# WHAT IS THE RELATIONSHIP BETWEEN DIETARY PATTERNS BEFORE AND DURING PREGNANCY AND GESTATIONAL AGE- AND SEX-SPECIFIC BIRTH WEIGHT?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between dietary patterns before and during pregnancy and gestational age- and sex-specific birth weight?

### What is the answer to the question?

- No conclusion can be drawn on the association between dietary patterns [underlined: during] pregnancy and birth weight outcomes. Although research is available, the ability to draw a conclusion is restricted by
  ○ inconsistency in study findings,
  ○ inadequate adjustment of birth weight for gestational age and sex, and
  ○ variation in study design, dietary assessment methodology, and adjustment of key confounding factors.
- Insufficient evidence exists to estimate the association between dietary patterns [underlined: before] pregnancy and birth weight outcomes. There are not enough studies available to answer this question.

### Why was this question asked?

- This important public health question was identified and prioritized as part of the U.S. Department of Agriculture and Department of Health and Human Services Pregnancy and Birth to 24 Months Project.

### How was this question answered?

- A team of Nutrition Evidence Systematic Review staff conducted a systematic review in collaboration with a group of experts called a Technical Expert Collaborative.

### What is the population of interest?

- Women who are pregnant or able to become pregnant, ages 15-44 years.

### What evidence was found?

- This review includes 21 studies.
- These studies assessed the relationship between dietary patterns before and during pregnancy and birth weight outcomes.
- Only one-third of studies used both gestational age- and sex -specific cut-off values when defining birth weight outcomes.
- Findings were highly inconsistent across this body of evidence.
- Roughly half of studies found no association between dietary patterns and birth weight outcomes.
- Those that did find an association were inconsistent in the direction of effect and dietary patterns measured.
- There are limitations in the evidence as follows: inconsistencies across different studies in terms of study design, how dietary patterns were assessed and adjustment of key confounders.
- Additional research is needed to assess the relationship between dietary patterns before and during pregnancy and gestational age- and sex-specific birth weight.

### How up-to-date is this review?

- This review includes literature from 01/1980 to 01/2017.

## FULL REVIEW

### Systematic review question

What is the relationship between dietary patterns before and during pregnancy and gestational age- and sex-specific birth weight?

### Conclusion statement

No conclusion can be drawn on the association between dietary patterns [underlined: during] pregnancy and birth weight outcomes. Although research is available, the ability to draw a conclusion is restricted by

- inconsistency in study findings,
- inadequate adjustment of birth weight for gestational age and sex, and
- variation in study design, dietary assessment methodology, and adjustment of key confounding factors.

### Grade

Grade not assignable

### Conclusion statement

Insufficient evidence exists to estimate the association between dietary patterns [underlined: before] pregnancy and birth weight outcomes. There are not enough studies available to answer this question.

### Grade

Grade not assignable

### Summary

- This systematic review includes18 prospective cohort, 1 retrospective cohort and 2 randomized control trials published between 1986 and 2016.
- The studies used multiple approaches to assess dietary patterns:
  ○ Nine studies used an index/score to assess dietary patterns.
  ○ Eight studies used factor/principal component analysis (PCA).
  ○ Two randomized controlled trials assigned subjects to one of two experimental diets.
  ○ One study did not use a formal method to arrive at a dietary pattern.
  ○ One study used both logistic regression and PCA.
- Many studies did not standardize for gestational age and/or infant sex when assessing birth weight.
  ○ Just one-third of studies (n=7) used both gestational age- and sex - specific cut-off values when defining small for gestational age (SGA), large for gestational age (LGA), appropriate for gestational age (AGA), or intrauterine growth restriction (IUGR).
  ○ Nine out of 21 studies reported birth weight, alone, without standardizing for gestational age or sex using z-scores.
- Study findings were highly inconsistent across the body of evidence. About half of studies (n=10) found no association between dietary patterns and birth weight outcomes. Among studies that observed an association, there was limited consistency in direction of effect and the dietary patterns generated.
- There are serious limitations to the generalizability of this review. Minority, lower-SES, and adolescent populations are underrepresented in the body of evidence.

### Description of the evidence

- The search included articles from very high and high Human Development Index (HDI) countries, and the search timeframe spanned between January 1980 and January 2017.
- This evidence review includes 18 prospective cohort studies, 1 retrospective cohort study and 2 RCTs that examined the relationship between dietary patterns before and during pregnancy and gestational age- and sex-specific birth weight.

As described in

- Table 1: Included trials and cohorts, a variety of cohorts and trials were represented in this body of evidence.

Table 1 Included trials and cohorts

Cohort/Trial Name | Study
1. Cardiovascular Risk Reduction Diet in Pregnancy (CARRDIP) trial | (1)
2. Generation R | (2, 3)
3. Australian Longitudinal Study on Women’s Health | (4)
4. Norwegian Mother and Child Cohort (MoBA) | (5)
5. Infant Feeding Practices Study (IFPS II) | (6)
6. INMA (Infancia y medio ambiente) and Rhea study | (7)
7. Valencia birth cohort (a sub-project of the INMA cohort) | (8)
8. Project Viva | (9)
9. Healthy Start Study | (10)
10. Growing up in Singapore Towards Healthy Outcomes Study (GUSTO) | (11)
11. CANDLE Study (Conditions Affecting Neurocognitive Development and Learning in Early Childhood) | (12)
12. Danish National Birth Cohort | (13)
13. Born in Guangzhou Cohort Study | (14)
14. Avon Longitudinal Study of Parents and Children | (15)
15. Osaka Maternal and Child Health Study | (16)
16. National Longitudinal Study of Adolescent Health (Add Health) | (17)
17. Unnamed cohort | (18–20)
18. Unnamed trial | (21)

- Seven of the 21 studies were conducted in the U.S (6, 9, 10, 12, 17, 18, 21). In addition, two studies were conducted in Spain (8, 19), one in Spain and Greece (7), two in Netherlands (2, 3), two in Australia (4, 20), two in Norway (1, 5), one in Denmark (13), one in Singapore (11), one in China (14), one in Japan (16) and one in England (15). See the map below.

This map illustrates the geographic distribution of settings for the included studies assessing the relationship between dietary patterns before and during pregnancy and gestational age- and sex-adjusted body weight.

#### Subject characteristics

- Sample size of the studies ranged from 12 subjects in a pilot study (21) to 66,597 subjects (5). The median sample size was 1,079.
- Age: Most of the studies included women between 20 and 40 years of age. An exception was the Add Health cohort, which included only adolescent participants (17). Monteagudo et al. reported that their study participants were between ages 21-46 years and the mean age was 31.9 years. Other studies noted that anywhere between 10% and 29% of the study participants were at least 35 years of age. The percentage of participants over 40 years was not specified, except by Knudsen et al. (1% of participants). The rest of the studies presented the mean age, which ranged from ~27 (12) to ~35 (21).
- Pregnancy characteristics: Almost all of the studies included singleton pregnancies, only.
- Health Characteristics:
  ○ One-third of studies excluded subjects with a previous diagnosis of type 1 and/or 2 diabetes mellitus (1, 5, 6, 10, 11, 14, 19). In addition, Shapiro et al. also excluded subjects with gestational diabetes in their index pregnancy.
  ○ A few studies included mother-baby dyads only if the baby was born within a specific time period:
    ■ Hillesund et al. included babies born between 37 and 42 weeks.
    ■ Poon et al. included children born at or after 35 weeks of gestation, but before 43.5 weeks. In addition, Poon et al. specified that only babies who weighed ≥5 lbs and didn’t stay in the intensive care unit for more than 3 days were included.
    ■ Shapiro et al. included all children with a gestational age ≥32 weeks.
    ■ Knudsen et al. included only full-term infants.
    ■ Lu et al. excluded preterm deliveries.
    ■ Okubo et al. included term deliveries born between 37 and 41 weeks of gestation.
  ○ A few studies excluded subjects with the following chronic diseases:
    ■ Hypertension (1, 8, 14, 19)
    ■ Thyroid pathology (19)
    ■ Asthma with active steroid management (10)
  ○ Timmermans et al. reported that 6% of their subjects had co-morbidities including chronic hypertension, heart disease, diabetes, high cholesterol, thyroid disease and systemic lupus erythematosus. Similarly, Chatzi noted that <3% of their study participants had gestational hypertension and <1% had diabetes before pregnancy.
  ○ Khoury et al. excluded women with high risk pregnancies caused by endocrine disease, history of thromboembolic disease or significant gastrointestinal, cardiac, pulmonary, or hematologic disease. Women with complications during a previous pregnancy, including neonatal death, still birth, and preterm delivery, were also excluded. Women who experienced ongoing hyperemesis gravidarum or bleeding after gestational week 12 in the current pregnancy were not included.
  ○ Okubo et al. reported that ~13% of their subjects had one or more of the following conditions: Hyperemesis, hydramnios, oligoamnios, gestosis, abruptio placenta, placenta previa, incompetent cervical os or others diagnosed by a medical doctor.
  ○ A few studies also excluded subjects with drug-abuse (1, 3) or serious psychiatric illness (10), or who were receiving psychotropic drugs (11).
  ○ Four studies excluded subjects whose pregnancies were conceived using assisted reproductive technologies (2, 3, 7, 8).
  ○ Two studies noted that their study participants were healthy or had a low risk pregnancy (12, 21).
- Smoking during pregnancy varied across studies:
  ○ Daily smoking ranged between ~3% (11) and 32% (20). Lu et al. reported that 30% experienced passive smoking.
  ○ Khoury et al. excluded current smokers from their study.
  ○ Pre-pregnancy smoking status (7-13 years prior to becoming pregnant) was reported to be 25% in one study (4).
- Race/ethnicity: About half of the studies (n=10) did not report participants’ race/ethnicity. Among the studies that did report this information:
  ○ One-third of studies noted that a majority of their subjects were white (Khoury: 100%; Grieger: 89%; Rodriguez-Bernal: 88%; Poon: 87%; Northstone: 82%; Rifas-Shiman: 72%; Shapiro: 55%). Categorized another way, Xie et al. noted that 77% of the study subjects were non-Blacks. Bouwland-Both et al. conducted their study in an all-Dutch population.
  ○ Only two studies reported including a majority of non-white subjects:
    ■ Colon-Ramos noted that 62% of their study participants were African American.
    ■ The GUSTO study participants (based in Singapore) were Chinese, Malayan or Indian. The authors did not specify the overall percentage of each race/ethnicity.
- Parity: There was heterogeneity in terms of study participants’ parity. For example, in some studies, most subjects were nulliparous (88% in Lu et al., 90% in Gresham et al. and 100% in Xie et al.). Other studies (n=11) reported that ~38% to 68% of women were nulliparous.
- Pre-pregnancy BMI:
  ○ In this body of evidence, Chia et al. reported one of the lowest mean pre-pregnancy BMIs (which ranged between 22.1 and 22.7 kg/m^2^, depending on the dietary pattern quintile). While Okubo et al. noted that the mean pre-pregnancy BMI was 20.2 kg/m^2^, it was based on maternal body weight measured at 20 years of age.
  ○ Colon-Ramos reported one of the highest mean pre-pregnancy BMI (~27.6 kg/m^2^), with the African American sub-group noting even higher mean BMI (28.8 kg/m^2^). The percentage of participants with BMI over 30 kg/m^2^ ranged from 4% (15) to 19% (10).
  ○ It should be noted that Khoury et al. excluded subjects with a BMI either <19 or >32 kg/m^2^.
  ○ While Grieger et al. reported on maternal BMI, it is unclear if it was measured pre-pregnancy.
  ○ Xie et al. reported that pre-pregnancy BMI in adolescents was 22.2 kg/m^2^.
- Maternal education: Among studies that reported maternal education (n=16), participants with more than a high school education ranged from 16% (19) to 91% (9).
- Socioeconomic status (SES) was reported in some of the studies (n=14). Data presented across studies were heterogeneous. Below are a few examples of studies that reported data on SES.
  ○ Kennedy noted that all of their participants were WIC eligible (income <185% of poverty level).
  ○ Poon noted that 38% had income <185% of poverty level.
  ○ Rifas-Shiman reported that 13% of their participants had income below $40,000, whereas Shapiro et al. reported that 29% of participants had income below $40,000.
  ○ Rodriguez-Bernal noted that 61% of their participants were manual workers. Meanwhile, Monteagudo et al. reported that 37% of participants were employed doing housework and 5% did agricultural work.
  ○ Grieger et al. reported that 82% of their participants were in the lowest 2/5^th^ SES strata.
  ○ Xie et al. study participants were adolescents, so they reported parental education status as a proxy for SES, with 79% of parents having at least a high school education.
  ○ Although Colon-Ramos did not report the SES of the study participants, the authors mentioned that the study was conducted in a U.S. county that was primarily low income (<200% poverty level).

#### Interventions/Exposures

Dietary patterns were assessed using 1) index/score analysis; 2) factor analysis and PCA; 3) experimental diet; 4) PCA and reduced rank regression; and 5) another unspecified method. A description of the studies included by each method used to measure dietary patterns is included below.

- Index/score analysis (Table 2: Indices and scores used to assess the relationship between dietary patterns before and during pregnancy and birth weight): Nine studies included in this review used one or more of the following indices/scores:
  ○ Mediterranean Diet Scale (7)
  ○ Australian Recommended Food Score (4)
  ○ New Nordic Diet score (5)
  ○ Nutritional Risk Score (18)
  ○ Mediterranean Diet Score for Pregnancy (19)
  ○ Alternative Mediterranean Diet (aMED) (6)
  ○ Alternative Healthy Eating Index for Pregnancy (6, 8, 9)
  ○ Healthy Eating Index-2010 (10)
- Factor analysis and PCA (Table 3: Summary of dietary patterns identified using factor or principal components analysis): Eight studies included in this review assessed dietary patterns using factor analysis or PCA (3, 11–16, 20)
- Experimental diet: Two studies included in this review assigned participants to one of two experimental diets (1, 21). Khoury et al. randomly assigned participants to the following diets:
  ○ Intervention diet:
    ■ Dietitians encouraged the intake of fatty fish, vegetable oils, especially olive oil and rapeseed oil, nuts, nut butters, margarine based on olive- or rapeseed oil, and avocado to replace meat, butter, cream, and fatty dairy products; the consumption of fresh fruits and vegetables was advised (at least 6 a day); intake of dairy products in the form of skimmed or low-fat products (skimmed milk, fat-reduced cheese, and yogurt) in place of full fat products was encouraged; subjects were advised to choose meat for a main meal twice a week and use legumes, vegetable main dishes, fatty fish, or poultry with the fat trimmed off on the other days; coffee was limited to 2 cups of filtered coffee a day
    ■ Compliance data showed that the intervention group included significantly more fish and fish products; fatty fish and fish products; rapeseed-based margarine; oils; olive oil; rapeseed oil; nuts, olives, and seeds; vegetables; and fruits when compared to the control diet^3^
  ○ Control diet:
    ■ Subjects were asked to consume their usual diet based on Norwegian foodstuffs, and not to introduce more oils or low-fat meat and dairy products [underlined: than usual]
    ■ Included significantly more fatty milk, meat and meat products, fatty minced meat, butter, and hard margarines [underlined: when compared to the intervention diet]^6^
  In a pilot RCT, Clapp randomly assigned participants to one of two experimental diets:
  ○ Aboriginal carbohydrate diet (Low-GI): used carbohydrates from unprocessed whole grains, fruits, beans, vegetables, and many dairy products; includes most dense whole grain and multigrain breads, bran cereals, pastas, fresh fruits and vegetables, yogurt, ice cream, and nuts
  ○ Cafeteria carbohydrate diet (High-GI): used carbohydrates from highly processed grains, root vegetables, and simple sugars; includes many highly-refined breads, potatoes, instant rice, most breakfast cereals, desserts, and snack-type foods.
- Logistic Regression and PCA: One study assessed adherence to a Mediterranean diet using logistic regression and PCA (2).
- Unspecified method: One study created dietary patterns by grouping foods into categories defined “on the basis of theoretical expectations” by Dube et al.^4^ and later used by Jeffery et al.^5^ and Agurs-Collins et al^6^ (17). The following three categories were created:
  ○ High-calorie sweet pattern: includes foods such as doughnuts, ice cream, chocolate candy, regular candy, and cookies
  ○ High-calorie nonsweet pattern: includes steak, fried chicken, fried fish, pizza, hot dogs, sausage, cheese, whole milk, etc.
  ○ Low-calorie pattern: includes foods such as low-fat and skim milk, grilled chicken, grilled fish, apples, and breakfast cereal

#### Time point of exposure

As described below, the time point of exposure and recall periods were heterogeneous across studies (Table 4: Time point of exposure assessment). The following section discusses the time period diet was assessed and the time window it represents.

- Before pregnancy:
  ○ Grieger et al. (20) collected data at 13 weeks, but the recall period was 12 months prior to conception.
  ○ Monteagudo et al. (19), Gresham et al. (4) and Xie et al. (17) did not specify a particular time period when the diet was assessed (which could have ranged from before to during pregnancy).
- First trimester: The following studies assessed diet during the first trimester, only:
  ○ Rodriguez-Bernal et al. (8)
  ○ Bouwland-Both et al. (3)
  ○ Timmermans et al. (2)
- Second trimester: The following studies assessed diet during the second trimester, only:
  ○ Hillesund et al. (5)
  ○ Chia et al. (11)
  ○ Colon-Ramos et al. (12)
  ○ Knudsen et al. (13)
  ○ Lu et al. (14)
- Third trimester: Northstone et al. (15) assessed diet during the third trimester, only.
- In the following studies, diet measurement spanned multiple trimesters -
  ○ Rifas-Shiman et al. (9) assessed maternal diet at two distinct time points: first trimester (11.7 ± 3.1 weeks) and second trimester (26 to 28 weeks)
  ○ Poon et al. (6) assessed diet in a window of 26 to 36 weeks.
  ○ Chatzi et al. (7) used multiple cohorts, with INMA collecting maternal diet data during the first trimester (~13.8 ± 2 weeks) and Rhea collecting dietary data between 14 and 18 weeks.
  ○ Shapiro et al. (10) collected dietary data one to eight times between 8 and 24 weeks.
  ○ Although Okubo et al. (16) collected data at around 18 weeks, the range spanned between 5 and 39 weeks.
  ○ Clapp (21) assigned diets randomly around 8 weeks and followed them until delivery.
  ○ Khoury et al. (1) assigned participants to one of two experimental diets between 17 and 20 weeks and followed them until delivery.
- The recall period varied from a few days (10, 11, 17) to a few weeks (13, 14) to a few months (2, 3, 5–9, 12, 16).

#### Outcomes

Studies assessed several outcomes including birth weight (reported in grams or kilograms), low birth weight, weight-for-length and weight-for-age z scores, macrosomia, SGA, AGA, LGA, body composition, and IUGR. Some studies also assessed fetal growth measures, including crown-rump length, estimated fetal weight, fetal head circumference, abdominal circumference, femur length, and placental resistance measured using pulsatility index umbilical artery and resistance index uterine artery. Many studies did not standardize for gestational age or sex when assessing birth weight (i.e., they used “raw” birth weight as the outcome across a range of preterm and term births). Specifically, one-third of studies (n=7) used both gestational age and sex-specific cut-off values when defining SGA, AGA, LGA and IUGR (1, 5, 6, 11, 13, 14, 16). Table 5: Summary of outcome definitions, summarizes the outcomes and diagnostic criteria grouped by methodology used to create dietary patterns.

Table 2 Indices and scores used to assess the relationship between dietary patterns before and during pregnancy and birth weight

Index/Score (Reference) | Mediterranean diet^10^ (min-max score) | Australian Recommended Food Score^11^ (min-max score) | New Nordic Diet Score^12,13^ | Nutritional Risk Score^14,15^ (min-max score)
Article | Chatzi et al., 2012 | Gresham et al., 2016 | Hillesund et al., 2014 | Kennedy, 1986
Component | Total score: 0-8 | Total score: 0-72 | Total score: 0-10 | Total score: 0-100
Vegetables | Vegetables; ≥Median = 1; <Median = 0 | Vegetables (0-22) | Root Vegetables; ≥Median = 1; <Median = 0 | Fruits and vegetables (0-30)
Vegetables | Vegetables; ≥Median = 1; <Median = 0 | Vegetables (0-22) | Cabbages; ≥Median = 1; <Median = 0 | Fruits and vegetables (0-30)
Vegetables | Vegetables; ≥Median = 1; <Median = 0 | Vegetables (0-22) | Potatoes relative to rice and pasta combined; ≥Median = 1; <Median = 0 | Fruits and vegetables (0-30)
Fruits | Fruits and nuts; ≥Median = 1; <Median = 0 | Fruits (0-14) | Nordic fruits; ≥Median = 1; <Median = 0 | Fruits included with vegetables above
Fruits | Fruits and nuts; ≥Median = 1; <Median = 0 | Fruits (0-14) | Native berries (includes “foods from wild countryside”) | Fruits included with vegetables above
Cereals/Grains and whole grains | Cereals; ≥Median = 1; <Median = 0 | Grains (0-14) | Whole grain bread; ≥Median = 1; <Median = 0 | Bread and cereal (0-15)
Cereals/Grains and whole grains | Cereals; ≥Median = 1; <Median = 0 | Grains (0-14) | Oatmeal porridge; ≥Median = 1; <Median = 0 | Bread and cereal (0-15)
Nuts and legumes | Legumes; ≥Median = 1; <Median = 0; Nuts included with fruits | See under fish and other protein foods | | Nuts, peanut butter, and legumes included under meat
Meat | Meat; ≥Median = 0; <Median = 1; (reverse scored) | Meat included as part of protein | | Meat or alternatives (0-40)
Fish and other protein foods | Fish and seafood; ≥Median = 1; <Median = 0 | Fish (0-2) | Foods from wild countryside (wild fish, seafood, game)^16^; Also includes native berries, captured as part of fruits; ≥Median = 1; <Median = 0 | Fish, liver, and eggs included as part of meat
Fish and other protein foods | Fish and seafood; ≥Median = 1; <Median = 0 | Meat (0-5) | Foods from wild countryside (wild fish, seafood, game)^16^; Also includes native berries, captured as part of fruits; ≥Median = 1; <Median = 0 | Fish, liver, and eggs included as part of meat
Fish and other protein foods | Fish and seafood; ≥Median = 1; <Median = 0 | Nuts/bean/soya (0-6) | Foods from wild countryside (wild fish, seafood, game)^16^; Also includes native berries, captured as part of fruits; ≥Median = 1; <Median = 0 | Fish, liver, and eggs included as part of meat
Fish and other protein foods | Fish and seafood; ≥Median = 1; <Median = 0 | Eggs (0-1) | Foods from wild countryside (wild fish, seafood, game)^16^; Also includes native berries, captured as part of fruits; ≥Median = 1; <Median = 0 | Fish, liver, and eggs included as part of meat
Dairy | Dairy products; ≥Median = 1; <Median = 0 | Dairy (0-7) | Milk; ≥Median = 1; <Median = 0 | Milk and cheese (0-15)
Fat | MUFA:SFA ratio; ≥Median = 1; <Median = 0 | Fat (0-1)
Empty calories
Fiber
Micronutrients
Sweetened beverages
Water | | | Water consumption relative to sweetened beverages; ≥Median = 1; <Median = 0
Alcohol | Excluded alcohol | Excluded alcohol

Index/Score (Reference) | Mediterranean Diet Score for Pregnancy^17^ | AHEI-P (min-max score)^18^ | Alternate Mediterranean Diet^19^ | AHEI-P (min-max score)^20^ | HEI-2010^21^
Article | Monteagudo et al., 2016 | Poon et al., 2013 | Poon et al., 2013 | Rifas-Shiman et al., 2009; Rodriguez-Bernal et al., 2010 | Shapiro et al., 2016
Component | Total score: 4-11 | Total score: 0-130 | Total score: 0-8 | Total score: 0-90 | Total score: 0-100
Vegetables | Vegetables; ≥Median = 1; <Median = 0 | Vegetables (0-10) | Vegetables; ≥Median = 1; <Median = 0 | Vegetables (0-10); (Includes tofu and soybeans) | Total vegetables (0-5); Greens and beans (0-5)
Fruits | Fruits and nuts; ≥Median = 1; <Median = 0 | Whole fruit (0-10) | Fruits; ≥Median = 1; <Median = 0 | Fruits (0 -10) | Total fruit (0-5)
Fruits | Fruits and nuts; ≥Median = 1; <Median = 0 | Whole fruit (0-10) | Fruits; ≥Median = 1; <Median = 0 | Fruits (0 -10) | Whole fruit (0-5)
Cereals/Grains and whole grains | Cereals; ≥Median = 1; <Median = 0 | Whole grains (0-10) | Whole grains; ≥Median = 1; <Median = 0 | | Whole grains (0-10)
Cereals/Grains and whole grains | Cereals; ≥Median = 1; <Median = 0 | Whole grains (0-10) | Whole grains; ≥Median = 1; <Median = 0 | | Refined grains (0-10); (reverse scored)
Nuts and legumes | Pulses; ≥Median = 1; <Median = 0 | Nuts and legumes (0-10) | Legumes; ≥Median = 1; <Median = 0 | | See fish and other protein foods below
Nuts and legumes | Nuts included with fruits | Nuts and legumes (0-10) | Nuts; ≥Median = 1; <Median = 0 | | See fish and other protein foods below
Meat | Meat; ≥Median = 0; <Median = 1; (reverse scored) | Red/processed meat - (10-0)^4^; (reverse scored) | Red and processed meats; ≥Median = 0; <Median = 1; (reverse scored) | Ratio of white (poultry/ fish) to red meat (beef, pork, lamb, processed) (0 -10); Excluded nuts and soy
Fish and other protein foods | Fish; ≥Median = 1; <Median = 0 | | Fish; ≥Median = 1; <Median = 0 | Included with meat | Total protein foods (0-5)
Fish and other protein foods | Fish; ≥Median = 1; <Median = 0 | | Fish; ≥Median = 1; <Median = 0 | Included with meat | Seafood and plant proteins (0-5)
Dairy | Dairy products; ≥Median = 0; <Median = 1; (reverse scored) | | | | Dairy (0-10)
Fat | MUFA:SFA ratio; ≥Median = 1; <Median = 0 | trans fat (10-0)^4^; (reverse scored) | MUFA:SFA ratio; ≥Median = 1; <Median = 0 | trans fat (0 - 10); (reverse scored) | Fatty acids (0-10)
Fat | MUFA:SFA ratio; ≥Median = 1; <Median = 0 | Long-chain (n= 3) fats (EPA + DHA) (0-10) | MUFA:SFA ratio; ≥Median = 1; <Median = 0 | PUFA:SFA ratio (0-10) | Fatty acids (0-10)
Fat | MUFA:SFA ratio; ≥Median = 1; <Median = 0 | PUFA (0-10) | MUFA:SFA ratio; ≥Median = 1; <Median = 0 | PUFA:SFA ratio (0-10) | Fatty acids (0-10)
Empty calories | | | | | Empty calories (0-20)
Fiber | | | | Fiber (0-10)
Micronutrients | Folic acid ≥2/3 RDI for pregnancy = 1; <2/3 RDI for pregnancy = 0 | Sodium (10-1)^4^; (reverse scored) | | Folate (0-10) | Sodium (0-10); (reverse scored)
Micronutrients | Iron ≥2/3 RDI for pregnancy = 1; <2/3 RDI for pregnancy = 0 | Calcium (0-10) | | Calcium (0-10) | Sodium (0-10); (reverse scored)
Micronutrients | Calcium ≥2/3 RDI for pregnancy = 1; <2/3 RDI for pregnancy = 0 | Folate (0-10) | | Iron (0-10) | Sodium (0-10); (reverse scored)
Micronutrients | Calcium ≥2/3 RDI for pregnancy = 1; <2/3 RDI for pregnancy = 0 | Iron (0-10) | | Iron (0-10) | Sodium (0-10); (reverse scored)
Sweetened beverages | | Sugar-sweetened beverages (10-0)^4^; (reverse scored)
Water
Alcohol | | Excluded alcohol | Excluded alcohol | Excluded alcohol | Excluded alcohol

Table 3 Summary of dietary patterns identified using factor or principal components analysis Study Dietary Patterns

Bouwland-Both, 2013 | Energy-rich pattern: high intakes of bread/breakfast cereals, margarine, nuts, snacks/sweets and nonsweetened nonalcoholic beverages; low intakes of sweetened, nonalcoholic beverages; Mediterranean pattern*: high intakes of vegetables, legumes, pasta/rice, dairy, fish/shellfish, vegetable oils, alcohol, nonsweetened nonalcoholic beverages; low intakes of processed meat; Western pattern*: high intakes of potatoes, pasta/rice, dairy, fresh meat, processed meat, margarine and alcohol; low intakes of nuts, fish/shellfish; *Mediterranean and Western dietary patterns showed no significant association with crown-rump length (CRL) and so were not included in the analysis
Chia, 2016 | Vegetable, fruit, and white rice pattern: characterized by higher intakes of vegetables, fruits, plain white rice, whole-grain bread, fish, and nuts and seeds and lower intakes of fried potatoes, burgers, carbonated and sweetened drinks, and flavored rice; Seafood and noodle pattern: higher intakes of soup, seafood, fish and seafood products, noodles (flavored and in soup), and low-fat red meat and lower intakes of legumes, ethnic bread, white rice, and curry-based gravies; Pasta, cheese, and processed meat pattern: characterized by high intakes of pasta-, tomato-, and cream-based gravies, cheese, and processed meat
Colón-Ramos, 2015 | Healthy pattern: high positive loadings for vegetables, fruits, non-fried fish and chicken, and water; Processed pattern: high positive loadings for processed meat, fast food items, snacks sweets, and soft drinks; Southern pattern: high positive loadings for cooked cereals, peaches, corn fried fish, beans, greens, pig’s feet, neck bones oxtails, tongue, and pork; Healthy-processed pattern: combination of these two DPs above; Healthy-southern pattern: combination of these two DPs above; Southern-processed pattern: combination of these two DPs above; Mixed pattern: foods from all other patterns together
Grieger, 2014 | High-protein/fruit pattern: fish, meat, chicken, fruit, whole grains; High-fat/sugar/takeaway pattern: takeaway foods, potato chips, refined grains, added sugar; Vegetarian-type pattern: vegetables, whole grains, legumes
Knudsen, 2008 | Western pattern: highest intake of high-fat dairy, refined grains, processed and red meat, animal fat (butter and lard), potatoes, sweets, beer, coffee, and high-energy drinks; lowest intake of fruits and vegetables (35% of energy intake from fat); Health conscious pattern: high intake of fruits, vegetables, fish, poultry, breakfast cereals, vegetable juice, and water; lowest intake of meat and fat of animal origin (25% of energy intake from fat); Intermediate pattern: high intake of low-fat dairy and fruit juice; consumption of the remaining food groups in between Western and Health conscious DPs (30% of energy intake from fat)
Lu, 2016 | Cereals, eggs, and Cantonese soups pattern: highest content of staples such as rice, pasta, porridge, eggs, and Cantonese soups; represents a traditional Cantonese diet; Dairy pattern: highest content of dairy; Fruits, nuts, and Cantonese desserts pattern: highest content of fruits, nuts, and Cantonese desserts; Meats pattern: highest content of red meat and processed meat; Vegetables pattern: highest content of leafy and cruciferous vegetables; Varied pattern: characterized by relatively high intakes of mixed food, including noodles, bread, root vegetables, melon vegetables, mushrooms, sea vegetables, bean vegetables, processed vegetables, poultry, animal organ meat, fish, other seafood, bean products, yoghourt, sweet beverages, puffed food, confectioneries, and snacks
Northstone, 2008 | Health-conscious pattern: high loadings on salad, fruit, rice, pasta, breakfast cereals, fish, eggs, pulses, fruit juices, poultry and non-white bread; Traditional pattern: high loadings on green vegetables and root vegetables, potatoes, peas and to some extent red meat and poultry; Processed pattern: high loadings on high-fat processed foods, such as meat pies, sausages and burgers, fried foods, pizza, chips and crisps; Confectionery pattern: characterized by high intakes of confectionery and other foods with high sugar content such as chocolate, sweets, biscuits, cakes and other puddings; Vegetarian pattern: loaded highly on meat substitutes, pulses, nuts and herbal tea and high negative loadings were seen with red meat and poultry
Okubo, 2012 | Meat and eggs pattern: high intake of beef and pork, processed meat, chicken, eggs, butter and dairy products; Wheat products pattern: high intake of bread, confectioneries, fruit and vegetable juice, and soft drinks; Rice, fish, and vegetables pattern: high intake of rice, potatoes, nuts, pulses, fruits, green and yellow vegetables, white vegetables, mushrooms, seaweeds, Japanese and Chinese tea, fish, shellfish, sea products, miso soup and salt-containing seasoning

Table 4 Time point of exposure assessment

Table 4 represents the time point at which the exposure was assessed and the time period that assessment represents for all studies looking at the association between dietary patterns before and during pregnancy and gestational age- and sex- adjusted birth weight.

Table 5 Summary of outcome definitions

Study | Outcome | Diagnostic Criteria | Source of Criteria | Method of Assessment | References | Additional Outcomes Measured
Index/Score
Chatzi, 2012 | Fetal growth restriction (weight, length, head circumference); Birth weight | FGR: birth weight <10th percentile of the predicted birth weight distribution | NR | Obtained from hospital delivery logs and medical records | NR | Birth length; Head circumference
Gresham, 2016 | Low birth weight | LBW: <2500g or 5.5lbs | NR | Self-reported | N/A | Gestational hypertension GDM Premature birth
Hillesund, 2014 | SGA, AGA, LGA; (Gestational age: 37-42 weeks) | SGA: <10th “gender-specific” birth weight percentile; LGA: >90th “gender-specific”^22^ birth weight percentile | NR | Newborn weight obtained from Medical Birth Registry of Norway and categorized by “gender-specific” cut-off values | N/A | Gestational weight gain
Kennedy, 1986 | Birth weight | LBW: <2500g | NR | Extracted from medical records | N/A | N/A
Monteagudo, 2016 | Birth weight (g) | N/A | N/A | Measured to the nearest gram by staff trained in using standard protocols (Lohman, 1988) | Lohman, 1988^23^ | N/A
Poon, 2013 | SGA; LGA; Birth weight (g); (Gestational age: ≥35 – ≤43.5 | SGA: ≤10th “gender-specific” birth weight for gestational age percentile; LGA: ≥90th “gender-specific”^24^ birth weight for gestational age percentile | Canadian reference for birth weight for gestational age | Reported on birth screener; Gestational age determined based on expected date of delivery and infant birth date | Kramer, 2001^25^ | Early infant growth (4-6 months)
Rifas-Shiman, 2009 | Birth weight for gestational age z-scores; SGA; LGA | SGA: <10th birth weight percentile; LGA: >90th birth weight percentile | Oken, 2003 | NR | Oken, 2003^26^ | Preeclampsia Gestational diabetes Gestational weight gain
Rodriguez-Bernal, 2010 | Fetal growth restriction Birth weight for gestational age (g) | FGR: below lower limit of confidence interval for growth potential predictions at 80% | Mamelle, 2006 | [underlined: FGR]; Estimated based on constitutional growth potential; [underlined: Birth weight]; Obtained from hospital delivery logs and medical records; Gestational age based on date of last menstrual period self-reported by the mothers and corrected by ultrasound | Mamelle, 2006^27^ | Birth length Head circumference
Shapiro, 2016 | Birth weight (g); (Gestational age: ≥32 weeks) | N/A | N/A | Results extracted from medical records | N/A | Birth length; Head circumference; Skin-fold thickness Neonatal body composition: fat mass and fat-free mass
PCA / Factor analysis
Bouwland-Both, 2013 | Crown-rump length Estimated fetal weight Birth weight (g) | N/A | N/A | [underlined: CRL]; Ultrasound; [underlined: EFW]; Calculated using Hadlock’s formula; [underlined: Birth weight]; Obtained from community midwife and hospital registries | Usher, 1969^28^ (standards for calculating GA & BW | Biomarkers of the one-carbon pathway (folate and total homocysteine in plasma and vitamin B12 in serum)
Chia, 2016 | Birth weight (g)SGA LGA | SGA: <10th percentile for gestational age (At 40 weeks of gestation, 2964 g for males, 2947 g for females); LGA: >90th percentile for gestational age (At 40 weeks of gestation, 3838 g for males; 3716 g for females) | Mikolajczyk, 2011 | Birth weight measured using a SECA 334 weighing scale to the nearest 1 g; retrieved from birth delivery reports; SGA and LGA determined using global birth-weight reference | Mikolajczyk, 2011^29^ | Preterm birth
Colon-Ramos, 2015 | Birth weight (weight-for-length and weight-for-age z-scores); (Gestational age ≥37 weeks) | N/A | N/A | Obtained from medical charts | N/A | Head circumference
Grieger, 2014 | Fetal birth weight (g) (LBW, SGA, IUGR, LGA, Macrosomia) | LBW: <2500 g and SGA; SGA: <10th percentile for gestational age; IUGR: <3rd percentile for gestational age; LGA: >90th percentile for gestational age; Macrosomia: >4000 g | NR | Collected at delivery (method NR) | N/A | Preterm birth
Knudsen, 2008 | Birth weight (g) (SGA) | SGA: z-score below the 2.5th percentile for respective sex and gestational age | Marsal, 1996 | Extracted from the National Patient Registry in Denmark | Marsal, 1996^30^ | N/A
Lu, 2016 | Birth weight (SGA, LGA) | SGA: birth weight <10th percentile of Guangzhou gestational age- and sex-specific reference growth curves; LGA: birth weight >90th percentile of Guangzhou gestational age- and sex-specific reference growth curves | Birthweight reference in Guangzhou | Birth weight and gestational age obtained from medical charts | He, 2014^31^ | N/A
Northstone, 2008 | Birth weight (g) | N/A | N/A | Recorded in delivery room; abstracted from birth notifications | N/A | N/A
Okubo, 2012 | Birth weight (g); (Gestational age: 37-41 weeks) | SGA: birth anthropometric measurements <10th percentile of the Japanese gestational age- and sex-specific reference growth curves | Ministry of Health, Labor, and Welfare or Japan | Self-administered questionnaire (Women were asked to refer to the neonatal anthropometric measurements recorded by the obstetrician or midwife in their Maternal and Child Health Handbook) | Ministry of Health, Labor, and Welfare of Japan, 2001^32^ | Birth length Head circumference Gestational weight gain
Other Method
Clapp, 1997 | Birth weight (kg) | N/A | N/A | Measured to the nearest 10g using a measurement box (Clapp, 1996) | Clapp, 1996^33^ | [underlined: Neonatal] Birth length Head circumference Abdominal circumference % body fat Fat mass (gm) Lean body mass (kg)
Khoury, 2005 | IUGR Birth weight (g) | IUGR: birth weight <10th percentile for gestational age and “gender”^34^ according to Norwegian percentiles | Norwegian percentiles | Obtained from hospital records | Skjærven, 2000^35^ | Maternal, cord, and neonatal cholesterol levels Hypertensive complications of pregnancy Preterm delivery Gestational weight gain
Timmermans, 2012 | Fetal size until birth (head circumference, abdominal circumference, femur length, estimated fetal weight); Placental resistance (pulsatility index umbilical artery, resistance index uterine artery); Birth weight (g) | IUGR^36^: gestational age-adjusted birth weight below percentile −2.3 in the study cohort (SD <-2.0) | NR | Fetal size (including IUGR): growth chart and constructed using fetal ultrasound measurements; Placental resistance: colour Doppler (Umbilical artery pulsatility index and Uterine artery resistance index); Birth weight: medical records | N/A | N/A
Xie, 2015 | Birth weight (kg) | N/A | N/A | Self-reported: Participants who had given birth were asked, “How much did the baby weigh at birth?” | N/A | Gestational age

### Evidence synthesis

With 21 included studies, there is a substantial body of evidence available to examine the relationship between dietary patterns before and during pregnancy and gestational age- and sex-adjusted birth weight. Table 6: Results grouped by methodology used for dietary pattern assessment, and the following section provide more information on the findings of each these studies. There is heterogeneity in the methodology employed to define and assess dietary patterns and in how outcomes were reported, which makes it difficult to compare across studies. Further, the time period of dietary assessment varied across studies.

#### Dietary patterns assessed via index/score

Nine studies used indices/scores to assess dietary patterns. Four of these studies found an association between adherence to a healthy dietary pattern and birth weight.

- Chatzi et al. (7) assessed maternal adherence to a Mediterranean Diet (MD) – characterized by vegetables, legumes, fruits and nuts, cereals, fish and seafood, dairy products, and the ratio of mono- to saturated lipids and all types of meat – in the context of fetal growth restriction and birth weight. The study included data from the multicenter INMA study (INMA-Atlantic and INMA-Mediterranean) and the RHEA study. Higher MD adherence in INMA-Mediterranean was associated with a lower risk of fetal growth restriction and higher birth weight. In the other two cohorts, there was no association between MD adherence and the outcomes.
- Gresham et al. (4) examined the association between adherence to the Australian Recommended Food Score (ARFS) before and during pregnancy and self-reported low birth weight. Components included vegetables, fruit, grain, protein (nuts/bean/soya, meat, fish, eggs), dairy, and fat. The exposure captured dietary intake during the previous 12 months. The time point of data collection ranged from before pregnancy to the end of the third trimester of pregnancy. The study found no significant difference in the odds of low birth weight based on adherence to the ARFS.
- Hillesund et al. (5) assessed maternal adherence to the New Nordic Diet (NND), which measured the frequency of eating the following foods: Nordic fruits (apples, pears, plums, strawberries), root vegetables (carrots, rutabaga and various types of onions), cabbages (kale, cauliflower, broccoli and Brussels sprouts), potatoes, whole grain breads, oatmeal porridge, foods from the wild countryside (wild fish, seafood, game and wild berries), milk and water. (The NND also measured the frequency of main meals per week.) High adherence to the NND, compared to low adherence, was associated with reduced odds of having an SGA baby and greater odds of having an LGA baby.
- Kennedy (18) examined the relationship between a nutritional risk score and birth weight. Components of the risk score included meat or alternatives (meats, fish, poultry, liver, eggs, nuts, peanut butter, legumes), milk and cheese, bread and cereal (whole grain, enriched, other), and four categories of fruits and vegetables (citrus and/or vitamin C-rich vegetables, green and yellow vegetables, all other including potato, and total fruits). The study found no association between nutritional risk score and birth weight.
- Monteagudo et al. (19) assessed the relationship between the Mediterranean Diet Score for Pregnancy (MDS-P) and birth weight. The components of MDS-P included vegetables, fruit and nuts, pulses, cereals, fish, ratio of monounsaturated to saturated fats, meat, dairy products and selected micronutrients (folic acid, iron, and calcium). A higher MDS-P score was a predictor of birth weight over 3,500 g.
- Poon et al. (6) assessed adherence to the Alternate Healthy Eating Index for Pregnancy (AHEI-P) and the Alternate Mediterranean Diet (aMED). AHEI-P was characterized by the following components: vegetables, whole fruit, whole grains, nuts and legumes, long-chain (n-3) fats, polyunsaturated fats, folate, calcium, iron, sugar-sweetened beverages, red and processed meat, trans fat, and sodium. aMED was characterized by vegetables, legumes, fruits, nuts, whole grains, fish, and the ratio of monounsaturated to saturated fats and red and processed meats. Adherence to the AHEI-P or aMED was not associated with birth weight or risk of SGA or LGA.
- Rifas-Shiman et al. (9) used an Alternate Healthy Eating Index modified for pregnancy (AHEI-P), which was characterized by intake of vegetables, fruit, ratio of white to red meat, fiber, trans fat, ratio of polyunsaturated to saturated fatty acids, and folate, calcium, and iron from foods. Greater adherence to the AHEI-P during the first or second trimester of pregnancy did not alter the risk of having an SGA or LGA baby.
- Rodriguez-Bernal et al. (8) assessed adherence to the Alternate Healthy Eating Index (AHEI) modified for pregnancy. Components of the AHEI included vegetables, fruit, nuts and soy, ratio of white meat (fish and poultry) to red meat, cereal fiber, trans fat, the ratio of polyunsaturated to saturated fat, and the intake of folate, calcium, and iron from foods. Higher adherence to the AHEI was associated with a lower risk of fetal growth restriction (estimated fetal weight) and improved birth weight.
- Shapiro et al. (10) used the Healthy Eating Index-2010 (HEI-2010) to assess diet quality during pregnancy. The components of HEI-2010 included total fruit, whole fruit, total vegetables, greens and beans, whole grains, dairy, total protein foods, seafood and plant proteins, fatty acids, refined grains, sodium and empty calories. Better maternal diet quality, defined as greater adherence to the HEI-2010 (score >57), was not associated with birth weight.

#### Dietary patterns assessed via factor or principal component analysis

Eight studies used data-driven methods (i.e., principal component analysis, exploratory factor analysis, and cluster analysis) to assess dietary patterns. Five of the eight studies found a relationship between diet and birth weight outcomes. A summary of findings from these studies is presented below.

- Bouwland-Both et al. (3) generated three dietary patterns. Higher adherence to the energy-rich dietary pattern (characterized by high intakes of bread/breakfast cereals, margarine, nuts, snacks/sweets and nonsweetened nonalcoholic beverages, and low intakes of sweetened, nonalcoholic beverages) was associated with a greater crown-rump length. However, the energy-rich dietary pattern was not associated with estimated fetal weight or birth weight. The Mediterranean and Western dietary patterns were not associated with crown-rump length and so were not included in further analyses.
- Chia et al. (11) showed that greater adherence to a vegetable, fruit and white rice dietary pattern (characterized by higher intakes of vegetables, fruits, plain white rice, whole-grain bread, fish, and nuts and seeds and lower intakes of fried potatoes, burgers, carbonated and sweetened drinks, and flavored rice) was associated with an increased risk of having LGA babies, but was not associated with having SGA babies. Chia et al. also assessed other dietary patterns (seafood and noodle and pasta, cheese and processed meat), which were not associated with birth weight or having SGA or LGA babies.
- Colon-Ramos et al. (12) generated three dietary patterns:
  ○ Healthy, characterized by high positive loadings for vegetables, fruits, non-fried fish and chicken, and water
  ○ Processed, characterized by high positive loadings for processed meat, fast food items, snacks sweets, and soft drinks
  ○ Southern, characterized by high positive loadings for cooked cereals, peaches, corn fried fish, beans, greens, pig’s feet, neck bones oxtails, tongue, and pork
  The authors also generated healthy-processed, healthy-Southern, Southern-processed, and mixed patterns, reflecting a combination of one or more of the above dietary patterns. None of these patterns were associated with weight-for-length and weight-for-age.
- Grieger et al. (20) measured dietary patterns before pregnancy. Three dietary patterns were generated:
  ○ High protein/fruit, characterized by a diet rich in fish, meat, chicken, fruit and whole grains
  ○ High fat, sugar/takeaway, characterized by takeaway foods, potato chips, refined grains, added sugar
  ○ Vegetarian type, characterized by a diet rich in vegetables, whole grains, legumes
  There was no association between any of these dietary patterns and the risk of having LBW or SGA babies.
- Knudsen et al. (13) used PCA to create three different dietary patterns:
  ○ Western pattern, including highest intake of high-fat dairy, refined grains, processed and red meat, animal fat (butter and lard), potatoes, sweets, beer, coffee, and high-energy drinks; lowest intake of fruits and vegetables (35% of energy intake from fat)
  ○ Health conscious pattern, including high intake of fruits, vegetables, fish, poultry, breakfast cereals, vegetable juice, and water; lowest intake of meat and fat of animal origin (25% of energy intake from fat)
  ○ Intermediate pattern, including high intake of low-fat dairy and fruit juice; consumption of the remaining food groups in between Western and Health conscious DPs (30% of energy intake from fat)
  When compared to a Western dietary pattern, adherence to an intermediate or health conscious dietary pattern was associated with lower odds of having an SGA baby.
- Lu et al. (14) generated the following dietary patterns using cluster analysis:
  ○ Cereals, eggs, and Cantonese soups pattern, with highest content of staples such as rice, pasta, porridge, eggs, and Cantonese soups; represents a traditional Cantonese diet
  ○ Dairy pattern, with highest content of dairy
  ○ Fruits, nuts, and Cantonese desserts pattern, with highest content of fruits, nuts, and Cantonese desserts
  ○ Meats pattern, with highest content of red meat and processed meat
  ○ Vegetables pattern, with highest content of leafy and cruciferous vegetables
  ○ Varied pattern, characterized by relatively high intakes of mixed food, including noodles, bread, root vegetables, melon vegetables, mushrooms, sea vegetables, bean vegetables, processed vegetables, poultry, animal organ meat, fish, other seafood, bean products, yoghourt, sweet beverages, puffed food, confectioneries, and snacks
  When compared to the cereals, eggs, and Cantonese soups pattern (representing a traditional Cantonese diet), none of the dietary patterns were significantly associated with birth weight for gestational age.
- Northstone et al. (15) used PCA to create the following dietary patterns:
  ○ Health-conscious pattern, with high loadings on salad, fruit, rice, pasta, breakfast cereals, fish, eggs, pulses, fruit juices, poultry and non-white bread
  ○ Traditional pattern, with high loadings on green vegetables and root vegetables, potatoes, peas and to some extent red meat and poultry
  ○ Processed pattern, with high loadings on high-fat processed foods, such as meat pies, sausages and burgers, fried foods, pizza, chips and crisps
  ○ Confectionery pattern, with high intakes of confectionery and other foods with high sugar content such as chocolate, sweets, biscuits, cakes and other puddings
  ○ Vegetarian pattern, loaded highly on meat substitutes, pulses, nuts and herbal tea and high negative loadings of red meat and poultry
  The health conscious dietary pattern was associated with higher birth weight, while the processed and vegetarian patterns were associated with lower birth weight. There was no association between the traditional and confectionery patterns and birth weight.
- Okubo et al. (16) used cluster analysis to create the following dietary patterns:
  ○ Meat and eggs pattern, characterized by high intake of beef and pork, processed meat, chicken, eggs, butter and dairy products
  ○ Wheat products pattern, characterized by high intake of bread, confectioneries, fruit and vegetable juice, and soft drinks
  ○ Rice, fish, and vegetables pattern, characterized by high intake of rice, potatoes, nuts, pulses, fruits, green and yellow vegetables, white vegetables, mushrooms, seaweeds, Japanese and Chinese tea, fish, shellfish, sea products, miso soup and salt-containing seasoning
  Adherence to the wheat products dietary pattern was associated with lower birth weight and a higher risk of SGA when compared to a rice, fish, and vegetable dietary pattern.

#### Dietary patterns assessed in the RCT

- Clapp (21) randomly assigned 12 subjects at 8 weeks of gestation to an aboriginal carbohydrate diet (a low glycemic index diet characterized by carbohydrates from unprocessed whole grains, fruits, beans, vegetables, and many dairy products) or a cafeteria carbohydrate diet (a high glycemic index diet characterized by carbohydrates from highly processed grains, root vegetables, and simple sugars). Mothers who were randomized to the cafeteria carbohydrate diet had babies with a greater mean birth weight when compared to those randomized to the aboriginal carbohydrate diet.
- Khoury et al. (1) randomly assigned 290 participants to an intervention or control diet. The intervention diet was characterized by higher amounts of fruits and vegetables, fatty fish, vegetable oils, nuts and low-fat dairy. Participants were asked to restrict meat and replace it with avocado, as well as to limit coffee consumption to 2 cups/day. Subjects who were assigned to the control group were asked to consume their usual diet based on Norwegian foodstuffs and not to introduce more oils or low-fat meat and dairy products than usual (1). There were no significant associations between diet and birth weight or risk of IUGR.

#### Dietary patterns assessed through other methods

- Timmermans et al. (2) used logistic regression to assess adherence to the Mediterranean dietary pattern, characterized by higher intakes of pasta, rice, vegetable oils, fish, vegetables and alcohol and lower intakes of meat, potatoes and fatty sauces. Compared to high adherence, low adherence was associated with lower fetal abdominal circumference during late pregnancy and lower estimated fetal weight during mid- and late-pregnancy. Similarly, medium and low adherence was associated with lower birth weight when compared to high adherence.
- Xie et al. (17) defined the following dietary patterns on the basis of theoretical expectations:
  ○ High-calorie, sweet pattern, characterized by foods such as doughnuts, ice cream, chocolate candy, regular candy, and cookies
  ○ High-calorie, non-sweet pattern, characterized by steak, fried chicken, fried fish, pizza, hot dogs, sausage, cheese, whole milk, etc.
  ○ Low-calorie pattern, characterized by foods such as low-fat and skim milk, grilled chicken, grilled fish, apples, and breakfast cereal
  The questionnaire was not validated, and the outcome was self-reported. In this adolescent-only cohort, there was no association between reported dietary patterns and birth weight.

Table 6 Results grouped by methodology used for dietary pattern assessment

Key for color-coding:
Dietary pattern categorized as beneficial when…; Greater adherence improves birth weight outcomes; Lower adherence is detrimental for birth weight outcomes
Dietary pattern categorized as detrimental when…; Greater adherence is detrimental for birth weight outcomes; Lower adherence improves birth weight outcomes

Author, Year; Country, N | Exposure | Outcome | Significant finding | NS finding
Index/Score
Before Pregnancy/Before and During Pregnancy
Gresham, 2016; Australia; N = 1,897 | Australian Recommended Food Score (ARFS); Based on consistency with Dietary Guidelines for Australian Adults and core foods within Australian Guide to Healthy Eating | Low birth weight (OR); Q1=REF | | Q2: 0.8 (95% CI: 0.3, 1.8); Q3: 0.8 (95% CI: 0.3, 1.8); Q4: 0.5 (95% CI: 0.2, 1.2); Q5: 0.4 (95% CI: 0.1, 1.1)
Monteagudo, 2016; Spain; N = 320 | Mediterranean Diet Score for Pregnancy (MDS-P); [underlined: Positively-scored components]: high consumption (median intake) of vegetables, fruit and nuts, pulses, cereals, and fish; a high MUFA:SFA ratio; low consumption of meat and dairy products; and the Spanish RDI of selected micronutrients (folic acid, Fe, and Ca), considering two-thirds of the RDI for pregnant women as the cut-off point | Birth weight (OR*); Lower=REF; *odds of weighing >3.5kg (third tertile) vs <2.5kg (first tertile) | Higher: 6.162 (95% CI: 1.438, 26.394)
Pregnancy
Chatzi, 2012; Spain; N = 2,461; Greece; N = 889 | Mediterranean Diet scale; [underlined: Positively scored components]: vegetables, legumes, fruits and nuts, cereals, fish and seafood, dairy products, and ratio of mono- to saturated lipids; [underlined: Negatively scored components]: all types of meat | Fetal growth restriction (RR); Low=REF | Spain (INMA-Mediterranean):; High: 0.50 (95% CI: 0.28, 0.90) | Spain (INMA-Mediterranean):; Medium: 0.76 (95% CI: 0.54, 1.06); Spain (INMA-Atlantic):; Medium: 1.24 (95% CI: 0.81, 1.89); High: 0.97 (95% CI: 0.42, 2.26); Greece:; Medium: 1.82 (95% CI: 0.95, 3.49); High: 1.96 (95% CI: 0.90, 4.25)
| | Birth weight (β); Low=REF | Spain (INMA-Mediterranean):; Medium: 55.20g (SE=23.52); High: 87.78g (SE=33.40) | Spain (INMA-Atlantic):; Medium: −26.46g (SE=26.03); High: −82.85g (SE=47.67); Greece:; Medium: −33.67g (SE=31.78); High: −20.42g (SE=42.33)
Hillesund, 2014; Norway; N = 66,597 | New Nordic Diet score; Constructed to measure adherence with the fundamental guidelines of the NND; [underlined: Positively-scored components]: (i) eating ≥24 main meals/week; (ii) eating Nordic fruits ≥5 times/week; (iii) eating root vegetables ≥5 times/week; (iv) eating cabbage ≥2 times/week; (v) eating potatoes ≥one-third of total occasions of eating potatoes, rice or pasta; (vi) choosing whole grain bread more often than refined bread; (vii) eating oatmeal ≥monthly; (viii) eating fish/game/berries about 2 times/week; (ix) drinking milk more often than juice; and (x) drinking ≥6 times as much water as sugar-sweetened beverages | SGA (OR); Low=REF | High: 0.92 (95% CI: 0.86, 0.99) | Medium: 0.95 (95% CI: 0.89, 1.02)
| | AGA (OR); Low=REF | | Medium: 1.00 (REF); High: 1.00 (REF)
| | LGA (OR); Low=REF | High: 1.07 (95% CI: 1.00, 1.15) | Medium: 1.04 (95% CI: 0.97, 1.12)
Kennedy, 1986; USA; N = 886 | Nutritional Risk score; Categorized as high, moderate, or low risk; [underlined: Positively-scored components]: meat or alternatives (meats, fish, poultry [fresh or processed], liver, eggs, nuts, peanut butter, legumes), milk and cheese (maximum of 3 oz of cheese scored), bread and cereal (whole grain, enriched, other), and fruits and vegetables (4 categories: citrus and/or vitamin C-rich vegetables, green and yellow vegetables, all other including potato, total fruits) | Birth weight (mean) | | High risk: 3,273g; Moderate risk: 3,262g; Low risk: 3,319 g
| | Low birth weight (%) | | High risk: 7.0%; Moderate risk: 6.9%; Low risk: 7.4%
Poon, 2013; USA; N = 893 | Alternative Healthy Eating Index for Pregnancy (AHEI-P); [underlined: Positively-scored components]: vegetables, whole fruit, whole grains, nuts and legumes, long-chain (n-3) fats, polyunsaturated fats, folate, calcium, and iron; [underlined: Negatively-scored components]: sugar-sweetened beverages, red and processed meat, trans fat, and sodium | SGA (RR); T1=REF | | T2: 0.73 (95% CI: 0.41, 1.31); T3: 0.93 (95% CI: 0.49, 1.75)
| | LGA (RR); T1=REF | | T2: 0.74 (95% CI: 0.43, 1.26); T3: 0.92 (95% CI: 0.50, 1.69)
| | Birth weight (mean difference in z-score units per unit increase in diet score) | | 0.002 (95% CI: −0.003, 0.008)
| Alternate Mediterranean Diet (aMED); [underlined: Healthier components]: vegetables, legumes, fruits, nuts, whole grains, fish, and the ratio of monounsaturated to saturated fats; [underlined: Less healthy components]: red and processed meats | SGA (RR); T1=REF | | T2: 0.75 (95% CI: 0.44, 1.29); T3: 0.94 (95% CI: 0.48, 1.81)
| | LGA (RR); T1=REF | | T2: 0.71 (95% CI: 0.44, 1.14); T3: 0.71 (95% CI: 0.37, 1.35)
| | Birth weight (mean difference in z-score units per unit increase in diet score) | | −0.003 (95% CI: −0.036, 0.031)
Rifas-Shiman, 2009; USA; N = 1,777 (first trimester); N = 1,666 (second trimester) | AHEI-P; vegetables; fruit; ratio of white to red meat; fiber; trans fat; ratio of polyunsaturated to saturated fatty acids; and folate, calcium, and iron from foods | SGA (OR); AGA=REF | | 1^st^ trimester:; 0.92 (95% CI: 0.82, 1.02); 2^nd^ trimester:; 1.00 (95% CI: 0.90, 1.10)
| | LGA (OR); AGA=REF | | 1^st^ trimester:; 0.95 (95% CI: 0.89, 1.02); 2^nd^ trimester:; 0.99 (95% CI: 0.92, 1.07)
Rodriguez-Bernal, 2010; Spain; N = 787 | AHEI-P; [underlined: Positively-scored components]: vegetables (5 serv/d); fruit (4 serv/d); nuts and soy (1 serv/d); ratio of white to red meat (≥4:1); cereal fiber (15g/d); trans fat (≤0.5% of energy); ratio of polyunsaturated to saturated fat (≥1); and folate (≥600g/d), calcium (≥1000mg/d), and iron (≥27mg/d) intakes from foods | Fetal growth restriction in weight (OR); Q1=REF | Q3: 0.35 (95% CI: 0.16, 0.76); Q4: 0.51 (95% CI: 0.26, 0.99); Q5: 0.24 (95% CI: 0.10, 0.55) | Q2: 0.55 (95% CI: 0.28, 1.08)
| | Birth weight adjusted for gestational age (β); Q1=REF | Q2: 92.69g (95% CI: 3.24, 182.16); Q4: 126.25g (95% CI: 38.53, 213.96); Q5: 114.15g (95% CI: 27.07, 201.23) | Q3: 83.45g (95% CI: −7.53, 174.43)
Shapiro, 2016; USA; N = 1,079 | Healthy Eating Index-2010 (HEI-2010):; [underlined: Components]: total fruit, whole fruit, total vegetables, greens and beans, whole grains, dairy, total protein foods, seafood and plant proteins, fatty acids, refined grains, sodium and empty calories | Birth weight (β); Score >57=REF | | Score ≤57: 27.86g (95% CI: −21.16, 76.89)
PCA/Factor Analysis
Before Pregnancy
Grieger, 2014; Australia; N = 309 | High-protein/fruit pattern; Fish, meat, chicken, fruit, whole grains | Low birth weight (OR for 1 SD increase in DP score) | | 0.41 (95% CI: 0.13, 1.33)
| | SGA (OR for 1 SD increase in DP score) | | 0.84 (95% CI: 0.55, 1.28)
| High-fat/sugar/takeaway pattern; Takeaway foods, potato chips, refined grains, added sugar | Low birth weight (OR for 1 SD increase in DP score) | | 1.39 (95% CI: 0.87, 2.22)
| | SGA (OR for 1 SD increase in DP score) | | 1.02 (95% CI: 0.72, 1.46)
| Vegetarian-type pattern; Vegetables, whole grains, legumes | Low birth weight (OR for 1 SD increase in DP score) | | 0.93 (95% CI: 0.54, 1.62)
| | SGA (OR for 1 SD increase in DP score) | | 1.16 (95% CI: 0.82, 1.64)
Pregnancy
Bouwland-Both, 2013; The Netherlands; N = 847 | Energy-rich pattern; [underlined: High] intakes of bread/breakfast cereals, margarine, nuts, snacks/sweets and nonsweetened nonalcoholic beverages;; [underlined: Low] intakes of sweetened, nonalcoholic beverages | Crown-rump length; Low=REF | Millimeters:; High: 1.62 (95% Ci: 0.52, 2.72); SD score:; High: 0.23 (95% Ci: 0.08, 0.38) | Millimeters:; Intermediate: 0.87 (95% CI: −0.23, 1.96); SD score:; Intermediate: 0.10 (95% CI: −0.05, 0.25)
| | Estimated fetal weight (β); Low=REF | | 2^nd^ trimester - SD score:; Intermediate: −0.01 (95% CI: −0.15, 0.12); High: 0.01 (95% CI: −0.12, 0.15); 3^rd^ trimester - SD score:; Intermediate: 0.11 (95% CI: −0.04, 0.26); High: 0.03 (95% CI: −0.12, 0.18)
| | Birth weight (β); Low=REF | | SD score:; Intermediate: 0.04 (95% CI: −0.14, 0.22); High: 0.10 (95% CI: −0.08, 0.28)
| Mediterranean pattern; [underlined: High] intakes of vegetables, legumes, pasta/rice, dairy, fish/shellfish, vegetable oils, alcohol, nonsweetened nonalcoholic beverages;; [underlined: Low] intakes of processed meat | N/A | N/A | Pattern showed no significant association with crown-rump length and so was not included in the analysis
| Western pattern; [underlined: High] intakes of potatoes, pasta/rice, dairy, fresh meat, processed meat, margarine and alcohol;; [underlined: Low] intakes of nuts, fish/shellfish | N/A | N/A | Pattern showed no significant association with crown-rump length and so was not included in the analysis
Chia, 2016; Singapore; N = 923 | Vegetable, fruit, and white rice pattern; [underlined: Higher] intakes of vegetables, fruits, plain white rice, whole-grain bread, fish, and nuts and seeds, and; [underlined: Lower] intakes of fried potatoes, burgers, carbonated and sweetened drinks, and flavored rice | Birth weight; (β per 1-SD increase in dietary pattern score) | | 29.47g (95% CI: −0.74, 59.67)
| | SGA (OR); Low=REF | | Higher: 1.03 (95% CI: 0.82, 1.30)
| | LGA (OR); Low=REF | Higher: 1.31 (95% CI: 1.06, 1.62)
| Seafood and noodle pattern; [underlined: Higher] intakes of soup, seafood, fish and seafood products, noodles (flavored and in soup), and low-fat red meat, and; [underlined: Lower] intakes of legumes, ethnic bread, white rice, and curry-based gravies | Birth weight; (β per 1-SD increase in dietary pattern score) | | 9.68g (95% CI: −22.90, 42.25)
| | SGA (OR); Low=REF | | Higher: 1.17 (95% CI: 0.92, 1.48)
| | LGA (OR); Low=REF | | Higher: 1.17 (95% CI: 0.92, 1.47)
| Pasta, cheese, and processed meat pattern; High intakes of pasta-, tomato-, and cream-based gravies, cheese, and processed meat | Birth weight; (β per 1-SD increase in dietary pattern score) | | 8.24g (95% CI: −19.12, 35.61)
| | SGA (OR); Low=REF | | Higher: 1.09 (95% CI: 0.89, 1.33)
| | LGA (OR); Low=REF | | Higher: 1.18 (95% CI: 0.99, 1.39)
Colón-Ramos, 2015; USA; N = 1,151 | Healthy pattern; High positive loadings for vegetables, fruits, non-fried fish and chicken, and water | Weight-for-length z-score (β); Healthy=REF | | REF
| | Weight-for-length z-score (β); Healthy=REF | | REF
| Processed pattern; High positive loadings for processed meat, fast food items, snacks sweets, and soft drinks | Weight-for-age z-score (β); Healthy=REF | | 0.23 (SE=0.19)
| | Weight-for-length z-score (β); Healthy=REF | | -0.03 (SE=0.14)
| Southern pattern; High positive loadings for cooked cereals, peaches, corn fried fish, beans, greens, pig’s feet, neck bones oxtails, tongue, and pork | Weight-for-age z-score (β); Healthy=REF | | -0.28 (SE=0.19)
| | Weight-for-length z-score (β) | | -0.07 (SE=0.14)
| Healthy-Processed pattern; Combination of these two DPs above | Weight-for-age z-score (β); Healthy=REF | | 0.16 (SE=0.16)
| | Weight-for-age z-score (β); Healthy=REF | | 0.12 (SE=0.11)
| Healthy-Southern pattern; Combination of these two DPs above | Weight-for-length z-score (β); Healthy=REF | | 0.17 (SE=0.19)
| | Weight-for-age z-score (β); Healthy=REF | | -0.09 (SE=0.14)
| Southern-Processed pattern; Combination of these two DPs above | Weight-for-length z-score (β); Healthy=REF | | -0.07 (SE=0.19)
| | Weight-for-age z-score (β); Healthy=REF | | -0.15 (SE=0.14)
| Mixed pattern; Foods from all other patterns together | Weight-for-length z-score (β); Healthy=REF | | 0.15 (SE=0.14)
| | Weight-for-age z-score (β); Healthy=REF | | -0.01 (SE=0.10)
Knudsen, 2008; Denmark; N = 44,612 | Western pattern; [underlined: Highest] intake of high-fat dairy, refined grains, processed and red meat, animal fat (butter and lard), potatoes, sweets, beer, coffee, and high-energy drinks;; [underlined: Lowest] intake of fruits and vegetables (35% of energy intake from fat) | SGA (OR); Western=REF | | 1.00 (REF)
| Health conscious pattern; [underlined: High] intake of fruits, vegetables, fish, poultry, breakfast cereals, vegetable juice, and water;; [underlined: Lowest] intake of meat and fat of animal origin; (25% of energy intake from fat) | SGA (OR); Western=REF | 0.74 (95% CI: 0.64, 0.86)
| Intermediate pattern; [underlined: High] intake of low-fat dairy and fruit juice;; Consumption of the remaining food groups in between Western and Health conscious DPs; (30% of energy intake from fat) | SGA (OR); Western=REF | 0.68 (95% CI: 0.55, 0.84)
Lu, 2016; China; N = 6,954 | Cereals, eggs, and Cantonese soups pattern; Highest content of staples such as rice, pasta, porridge, eggs, and Cantonese soups; represents a traditional Cantonese diet | SGA (OR); Cereals, eggs, and Cantonese soups =REF | | 1.00 (REF)
| | LGA (OR); Cereals, eggs, and Cantonese soups =REF | | 1.00 (REF)
| Dairy pattern; Highest content of dairy | SGA (OR); Cereals, eggs, and Cantonese soups =REF | | 0.87 (95% CI: 0.63, 1.21)
| | LGA (OR); Cereals, eggs, and Cantonese soups =REF | | 1.01 (95% CI: 0.75, 1.35)
| Fruits, nuts, and Cantonese desserts pattern; Highest content of fruits, nuts, and Cantonese desserts | SGA (OR); Cereals, eggs, and Cantonese soups =REF | | 0.76 (95% CI: 0.53, 1.10)
| | LGA (OR); Cereals, eggs, and Cantonese soups =REF | | 1.14 (95% CI: 0.84, 1.54)
| Meats pattern; Highest content of red meat and processed meat | SGA (OR); Cereals, eggs, and Cantonese soups =REF | | 0.95 (95% CI: 0.69, 1.30)
| | LGA (OR); Cereals, eggs, and Cantonese soups=REF | | 0.75 (95% CI: 0.56, 1.02)
| Vegetables pattern; Highest content of leafy and cruciferous vegetables | SGA (OR); Cereals, eggs, and Cantonese soups=REF | | 0.77 (95% CI: 0.56, 1.05)
| | LGA (OR); Cereals, eggs, and Cantonese soups=REF | | 1.03 (95% CI: 0.79, 1.36)
| Varied pattern; Relatively high intakes of mixed food, including noodles, bread, root vegetables, melon vegetables, mushrooms, sea vegetables, bean vegetables, processed vegetables, poultry, animal organ meat, fish, other seafood, bean products, yoghourt, sweet beverages, puffed food, confectioneries, and snacks | SGA (OR); Cereals, eggs, and Cantonese soups=REF | | 0.77 (95% CI: 0.57, 1.04)
| | LGA (OR); Cereals, eggs, and Cantonese soups=REF | | 1.10 (95% CI: 0.85, 1.42)
Northstone, 2008; England; N = 12,053 | Health-conscious pattern; High loadings on salad, fruit, rice, pasta, breakfast cereals, fish, eggs, pulses, fruit juices, poultry and non-white bread | Birth weight; (β per 1 SD increase in DP score) | 39.87g (95% CI: 29.59, 50.16)
| Traditional pattern; High loadings on green vegetables and root vegetables, potatoes, peas and to some extent red meat and poultry | Birth weight; (β per 1 SD increase in DP score) | | 6.63g (95% CI: −3.40, 16.66)
| Processed pattern; High loadings on high-fat processed foods, such as meat pies, sausages and burgers, fried foods, pizza, chips and crisps | Birth weight; (β per 1 SD increase in DP score) | −18.03g (95% CI: −29.74, −6.33)
| Confectionery pattern; High intakes of confectionery and other foods with high sugar content such as chocolate, sweets, biscuits, cakes and other puddings | Birth weight; (β per 1 SD increase in DP score) | | −1.25g (95% CI: −12.90, 10.41)
| Vegetarian pattern; Loaded highly on meat substitutes, pulses, nuts and herbal tea and high negative loadings were seen with red meat and poultry | Birth weight; (β per 1 SD increase in DP score) | −15.47g (95% CI: −25.44, −5.50)
Okubo, 2012; Japan; N = 803 | Meat and eggs pattern; High intake of beef and pork, processed meat, chicken, eggs, butter and dairy products | Birth weight (mean) | | 3,105g (95% CI: 3,069, 3,141)
| | SGA (OR); Rice, fish, and vegetables=REF | | 4.32 (95% CI: 0.92, 20.3)
| Wheat products pattern; High intake of bread, confectioneries, fruit and vegetable juice, and soft drinks | Birth weight (mean) | 3,073g (95% CI: 3,063, 3,111)*; *significantly different than rice, fish, and vegetables pattern
| | SGA (OR); Rice, fish, and vegetables=REF | 5.24 (95% CI: 1.13, 24.4)
| Rice, fish, and vegetables pattern; High intake of rice, potatoes, nuts, pulses, fruits, green and yellow vegetables, white vegetables, mushrooms, seaweeds, Japanese and Chinese tea, fish, shellfish, sea products, miso soup and salt-containing seasoning | Birth weight (mean) | 3,153g (95% CI: 3,104, 3,203)*; *significantly different than wheat products pattern
| | SGA (OR); Rice, fish, and vegetables=REF | | 1.00 (REF)
Other Method
Before Pregnancy/Before and/or During Pregnancy
Xie, 2015; USA; N = 572 | High-calorie sweet pattern; Foods such as doughnuts, ice cream, chocolate candy, regular candy, and cookies | Birth weight; (β for 1-unit increase in the scale) | | 0.02 kg (SE= 0.02)
| High-calorie nonsweet pattern; Steak, fried chicken, fried fish, pizza, hot dogs, sausage, cheese, whole milk, etc. | Birth weight; (β for 1-unit increase in the scale) | | -0.004 kg (SE= 0.01)
| Low-calorie pattern; Foods such as low-fat and skim milk, grilled chicken, grilled fish, apples, and breakfast cereal | Birth weight; (β for 1-unit increase in the scale) | | 0.03 kg (SE= 0.03)
Pregnancy
Clapp, 1997; USA; N = 12 | Aboriginal Carbohydrate Diet (Low-GI); Carbs from unprocessed whole grains, fruits, beans, vegetables, and many dairy products; includes most dense whole grain and multigrain breads, bran cereals, pastas, fresh fruits and vegetables, yogurt, ice cream, and nuts | Birth weight; (mean ± SEM) | 3.27 ± 0.12 kg*; *significantly different than cafeteria carbohydrate diet
| Cafeteria Carbohydrate Diet (High-GI); Carbs from highly processed grains, root vegetables, and simple sugars; includes many highly refined breads, potatoes, instant rice, most breakfast cereals, desserts, and snack-type foods | Birth weight (mean ± SEM) | 4.25 ± 0.11 kg*; *significantly different than aboriginal carbohydrate diet
Khoury, 2005; Norway; N = 290 | Intervention diet; Dietician encouraged the intake of fatty fish, vegetable oils, especially olive oil and rapeseed oil, nuts, nut butters, margarine based on olive- or rapeseed oil, and avocado to replace meat, butter, cream, and fatty dairy products; the consumption of fresh fruits and vegetables was advised (at least 6 a day); intake of dairy products in the form of skimmed or low-fat products (skimmed milk, fat-reduced cheese, and yogurt) in place of full fat products was encouraged; subjects were advised to choose meat for a main meal twice a week and use legumes, vegetable main dishes, fatty fish, or poultry with the fat trimmed off on the other days; coffee was limited to 2 cups of filtered coffee a day; - included significantly more fish and fish products; fatty fish and fish products; rapeseed-based margarine; oils; olive oil; rapeseed oil; nuts, olives, and seeds; vegetables; and fruits when compared to the control diet; See below for control diet description; Control diet; Subjects asked to consume their usual diet based on Norwegian foodstuffs, and not to introduce more oils or low-fat meat and dairy products than usual; - included significantly more fatty milk, meat and meat products, fatty minced meat, butter, and hard margarines when compared to the intervention diet | Birth weight | | Mean difference: 42.9g (95% CI: −89.3, 175); Control: 3542g ± 647; Intervention: 3579g ± 649
| | Birth weight (excluding subjects who gave birth before week 37) | | Mean difference: NR (95% CI: NR; P = .2); Control: 3664g ± 480; Intervention: 3596g ± 474
| Control diet vs Intervention diet | Intrauterine growth restriction (OR); Control=REF | | Intervention: 1.0 (95% CI: 0.4, 2.5)
Timmermans, 2012; The Netherlands; N = 3,207 | Mediterranean diet; Higher intakes of pasta, rice, vegetable oils, fish, vegetables and alcohol, and lower intakes of meat, potatoes and fatty sauces (r >0.20) | Resistance index uterine artery (β); High=REF | | Medium: 0.02 (95% CI: −0.00, 0.03); Low: 0.01 (95% CI: −0.00, 0.03)
| | Head circumference standard deviation score (β); High=REF | | Mid-pregnancy:; Medium: 0.01 (95% CI: −0.08, 0.10); Low: 0.01 (95% CI: −0.09, 0.10); Late-pregnancy:; Medium: −0.03 (95% CI: −0.12, 0.05); Low: −0.08 (95% CI: −0.17, 0.01)
| | Abdominal circumference standard deviation score (β); High=REF | Late-pregnancy:; Low: −0.16 (95% CI: −0.25, −0.07) | Mid-pregnancy:; Medium: −0.03 (95% CI:−0.12, 0.06); Low: −0.05 (95% CI: −0.14, 0.04); Late-pregnancy:; Medium: −0.06 (95% CI:−0.15, 0.03)
| | Femur length standard deviation score (β); High=REF | | Mid-pregnancy:; Medium: 0.02 (95% CI:−0.06, 0.11); Low: 0.07 (95% CI: −0.02, 0.16); Late-pregnancy:; Medium: 0.00 (95% CI:−0.08, 0.08); Low: 0.01 (95% CI: −0.08, 0.09)
| | Estimated fetal weight standard deviation score (β); High=REF | Mid-pregnancy:; Low: −0.01 (95% CI: −0.09, −0.08); Late-pregnancy:; Low: −0.11 (95% CI: −0.20, −0.02) | Mid-pregnancy:; Medium: 0.08 (95% CI:−0.08, 0.09); Late-pregnancy:; Medium: −0.07 (95% CI:−0.16, 0.02)
| | Birth weight (β); High=REF | Medium: −58.0g (95% CI: −95.8, −20.3); Difference in SDS: −0.16 (95% CI: −0.24, −0.07); Low: −72.0g (95% CI: −110.8, −33.3); Difference in SDS: −0.21 (95% CI: −0.30, −0.12)

#### Assessment of the body of evidence

A grade was not assignable for this body of evidence. The individual grading elements are discussed below.

#### Internal validity (determined with the NEL Bias Assessment Tool)

- Study Design: The data were primarily observational in nature, making it difficult to determine causal effect of the dietary patterns. Further, the characteristics of the study participants were also heterogeneous.
- Exposure:
  ○ Data were primarily self-reported, thus possibly affecting the validity of the data collected.
  ○ Studies used a variety of tools to measure participants’ dietary intake:
    ■ Food frequency questionnaires (FFQ) were the primary measurement tool. A few of the FFQ used were neither validated (15, 17, 18) nor assessed for reliability, and the type of FFQ used varied between studies.
    ■ Some studies used other methods, including diet history questionnaires (6, 10), 24-hr recall (10), a 3-day food diary (11) and dietary recall (17).
    ■ When the subjects were randomized to a particular diet, compliance was assessed periodically (1, 21).
  ○ Furthermore, the methods used to create dietary patterns were heterogeneous.
- Timing:
  ○ Variation in the timing of exposure assessment and the duration of recall periods across studies makes it difficult to draw conclusions for the entire periods before and during pregnancy.
    ■ Grieger et al. exclusively assessed maternal diet before pregnancy.
    ■ Monteagudo et al., Gresham et al. and Xie et al. measured diet during a wide window spanning from before pregnancy to the end of pregnancy, and they did not delineate their findings based on timing (before pregnancy vs. during pregnancy).
    ■ Rodriguez-Bernal et al., Bouwland-Both et al. and Timmermans et al. assessed diet during the first trimester, with the recall period spanning from conception until the point of measurement.
    ■ Hillesund et al., Chia et al., Colon-Ramos et al., Knudsen et al., and Lu et al. all measured maternal diet during the second trimester (with variable time periods of recall).
    ■ Northstone et al. measured diet during the third trimester and captured current consumption.
    ■ Several studies assessed diet across trimesters, which included varied recall periods.
- Confounders:
  ○ Key confounders (parity, educational attainment, smoking status, race/ethnicity, maternal age, family poverty income ratio, pre-pregnancy BMI, mean total energy intake, and hypertensive disorders of pregnancy) were not consistently accounted for across studies. This limits the internal validity of study findings.
    ■ Six studies did not adjust for pre-pregnancy BMI, two of which were RCTs. Khoury et al. noted that pre-pregnancy BMI did not differ between intervention and control diet groups, whereas Clapp did not compare pre-pregnancy BMI across groups.
    ■ Furthermore, only six of 21 studies adjusted for maternal energy intake, a key confounder in the association between dietary patterns and birth weight outcomes.
  ○ None of the studies included in this review assessed effect measure modification between dietary patterns and maternal pre-pregnancy BMI in the context of birth weight outcomes. Failing to examine these potential interactions could have prevented these studies from observing associations.
- Outcome:
  ○ Outcomes were assessed in a variety of ways across studies included in this review.
    ■ Just one-third of studies (n=7) used both gestational age- and sex-specific cut-off values when defining SGA, AGA, LGA and IUGR (1, 5, 6, 11, 13, 14, 16).
    ■ Twelve studies reported birth weight adjusted for gestational age as an outcome (1, 5–9, 11–14, 16, 20).
    ■ Nine studies reported birth weight, alone, without standardizing for gestational age or sex or using z-scores (2–4, 10, 15, 17–19, 21).
  ○ Four studies included subjects born at a specified gestational age:
    ■ Hillesund (≥ 37 to ≤42 weeks)
    ■ Poon (≥35 to ≤ 43.5 weeks)
    ■ Shapiro (≥32 weeks)
    ■ Okubo (≥37 to ≤41 weeks)
  ○ The use of birth weight values unadjusted for infant sex or gestational age at delivery in many of these studies makes these data difficult to interpret.

#### Consistency

- There was heterogeneity in study findings in this body of evidence. Some studies found an association between dietary patterns and birth weight outcomes (n = 11), while others did not (n=10). This varied by the specific measure of size at birth that was used in each study.
- Small- or large-for-gestational age:
  ○ Five of the 12 studies showed an association between dietary patterns and SGA (5, 7, 8, 13, 16).
  ○ Two of the six studies noted that a greater adherence to a dietary pattern (specifically, the New Nordic Diet and a vegetable, fruit and white rice pattern) was associated with an increased risk of LGA (5, 11). Monteagudo et al. observed that a higher Mediterranean diet score was predictive of newborn overweight (>3,500 g) when compared to newborn underweight (<2,500g); however, the birth weight was not standardized for gestational age or z-score.
    ■ Monteagudo et al. findings may be explained in part by their structuring of the outcome as the likelihood of overweight versus underweight as the reference group. This likely contributed to their large observed effect size.
- Birth weight:
  ○ Birth weight standardized for gestational age was reported in three studies (8, 9, 12), of which only Rodriguez-Bernal et al. reported a positive association with the birth weight.
  ○ Crude birth weight, without standardizing for gestational age or sex (i.e, using percentiles or z-scores), was reported in 9 studies. Of these, four showed that adherence to a healthy dietary pattern was associated with birth weight (2, 7, 15, 21). Among studies that reported low birth weight as an outcome (n=3), none showed an association with maternal dietary patterns (4, 18, 20).
  ○ The mean birth weight for included studies was above 3,000 g (range: 3,103 g (16) to ~3,760 g (21)), indicating that babies were born at a healthy weight, overall. This may explain why many studies did not detect an association between healthier dietary patterns and increased birth weight.
- Dietary patterns were associated with other outcomes such as crown-rump length (3), estimated fetal weight during mid- and late-pregnancy and late-pregnancy abdominal circumference (2), but there was no association with other fetal measures (head circumference, femur length) or weight for length z-score.

#### Impact

- Most of the studies in the body of evidence directly examined the relationship between different dietary patterns or different levels of adherence to a dietary pattern and birth weight. However, there were a few exceptions. First, the RCT by Khoury et al. assessed IUGR and birth weight as secondary outcomes. The primary study was focused on understanding the relationship between a cholesterol-lowering diet during pregnancy and maternal, cord, and neonatal cholesterol levels (1). Second, Shapiro et al. was designed to assess the association between maternal diet and neonatal adiposity, with birth weight as a secondary outcome.
- The lack of consistency across studies limits the practical/clinical significance of this review.

#### Adequacy

- A substantial number of studies were included in this review. The evidence base included 21 studies comprising 2 RCTs, 18 prospective cohort studies, and 1 retrospective cohort study.
- Most of the studies were conducted by independent research groups. The only exception was Timmermans et al. and Bouwland-Both et al., who both used data from the Generation R study and also had overlapping authorship.
- Sample sizes varied from 12 subjects to 66,597 subjects. The median sample size was 1,079. None of the studies reported power calculations. A few studies (1, 17, 19–21) had lower sample sizes, which might have limited their ability to detect significant differences had such differences been present.

#### Generalizability

- There are serious limitations to the generalizability of these findings.
  ○ Only seven out of 21 studies were conducted in the U.S.
  ○ Adolescent, minority, and lower-SES populations are underrepresented in the body of evidence. Only one study was conducted primarily in adolescent girls (17).
- It is unknown if the findings would apply to more diverse samples before and during pregnancy.

#### Other limitations/considerations

Many of the studies did not use a standardized outcome measure (such as SGA, LGA, or gestational age- and sex-specific birth weight). Even among those that used a standardized measure, there was heterogeneity in how it was defined. Some studies used observed distributions of fetal size that are standardized for gestational age and sex in a defined population. Meanwhile, others used observed distributions that were customized based on maternal characteristics (e.g. maternal parity, height, ethnicity) or standards derived from a healthy population selected to reflect optimal growth^37^.

As discussed above, none of the studies assessed effect measure modification between dietary patterns and maternal pre-pregnancy BMI in the context of birth weight outcomes and only a limited number of studies (n=6) adjusted for mean total energy intake. These limitations could have possibly influenced the study findings.

Many different methods (sometimes using the same nomenclature) were used to define and assess dietary patterns, making it difficult to compare or contrast results across studies. Journal editors and peer-reviewers may be less willing to publish studies that replicate others’ findings, which could have resulted in an evidence base with a wide array of dietary patterns. It is important for the editors and peer-reviewers to understand the need for publishing studies that replicate dietary patterns, in addition to publishing studies that assess unique dietary patterns.^38^

### Research recommendations

To assess the relationship between dietary patterns before and during pregnancy and birth weight outcomes more adequately, additional research is needed that should:

- Include diverse populations from the U.S. and elsewhere with varying age groups (including adolescents) and different racial/ethnic and socioeconomic backgrounds.
- Assess effect measure modification by pre-pregnancy BMI and gestational weight gain.
- Use a standardized birth size measure (such as one developed by the INTERGROWTH-21^st^ project) that would enable valid comparisons between and within countries^39^.
- Include well-designed and sufficiently powered RCTs.
- Foster collaborative efforts across different regions and populations so that dietary patterns can be more consistently scored, compared and reproduced across studies.
- Develop and validate novel epidemiological tools that can accurately capture the complexity of dietary habits.
- Promote harmonization of research methods across various cohorts and randomized trials, similar to the National Cancer Institute’s Dietary Patterns Methods Project^40^.
- Adjust for key confounding factors in observational studies, including parity, educational attainment, smoking status, race/ethnicity, maternal age, family poverty income ratio, pre-pregnancy BMI, mean total energy intake and gestational weight gain.

### Included articles

1 Khoury J, Henriksen T, Christophersen B, Tonstad S. Effect of a cholesterol-lowering diet on maternal, cord, and neonatal lipids, and pregnancy outcome: a randomized clinical trial. Am J Obstet Gynecol 2005;193(4):1292–301.16202717
2 Timmermans S, Steegers-Theunissen RP, Vujkovic M, den Breeijen H, Russcher H, Lindemans J, Mackenbach J, Hofman A, Lesaffre EE, Jaddoe VV, . The Mediterranean diet and fetal size parameters: the Generation R Study. Br J Nutr 2012;108(8):1399–409.22348517
3 Bouwland-Both MI, Steegers-Theunissen RP, Vujkovic M, Lesaffre EM, Mook-Kanamori DO, Hofman A, Lindemans J, Russcher H, Jaddoe VW, Steegers EA. A periconceptional energy-rich dietary pattern is associated with early fetal growth: the Generation R study. BJOG 2013;120(4):435–45.23194298
4 Gresham E, Collins CE, Mishra GD, Byles JE, Hure AJ. Diet quality before or during pregnancy and the relationship with pregnancy and birth outcomes: the Australian Longitudinal Study on Women’s Health. Public Health Nutr 2016;19(16):2975–83.27238757
5 Hillesund ER, Bere E, Haugen M, Overby NC. Development of a New Nordic Diet score and its association with gestational weight gain and fetal growth - a study performed in the Norwegian Mother and Child Cohort Study (MoBa). Public Health Nutr 2014;17(9):1909–18.24685309
6 Poon AK, Yeung E, Boghossian N, Albert PS, Zhang C. Maternal Dietary Patterns during Third Trimester in Association with Birthweight Characteristics and Early Infant Growth. Scientifica (Cairo) 2013;2013:786409.24490111
7 Chatzi L, Mendez M, Garcia R, Roumeliotaki T, Ibarluzea J, Tardon A, Amiano P, Lertxundi A, Iniguez C, Vioque J, . Mediterranean diet adherence during pregnancy and fetal growth: INMA (Spain) and RHEA (Greece) mother-child cohort studies. Br J Nutr 2012;107(1):135–45.21733314
8 Rodriguez-Bernal CL, Rebagliato M, Iniguez C, Vioque J, Navarrete-Munoz EM, Murcia M, Bolumar F, Marco A, Ballester F. Diet quality in early pregnancy and its effects on fetal growth outcomes: the Infancia y Medio Ambiente (Childhood and Environment) Mother and Child Cohort Study in Spain. Am J Clin Nutr 2010;91(6):1659–66.20410088
9 Rifas-Shiman SL, Rich-Edwards JW, Kleinman KP, Oken E, Gillman MW. Dietary quality during pregnancy varies by maternal characteristics in Project Viva: a US cohort. J Am Diet Assoc 2009;109(6):1004–11.19465182
10 Shapiro AL, Kaar JL, Crume TL, Starling AP, Siega-Riz AM, Ringham BM, Glueck DH, Norris JM, Barbour LA, Friedman JE, . Maternal diet quality in pregnancy and neonatal adiposity: the Healthy Start Study. Int J Obes (Lond) 2016;40(7):1056–62.27133623
11 Chia AR, de Seymour JV, Colega M, Chen LW, Chan YH, Aris IM, Tint MT, Quah PL, Godfrey KM, Yap F, . A vegetable, fruit, and white rice dietary pattern during pregnancy is associated with a lower risk of preterm birth and larger birth size in a multiethnic Asian cohort: the Growing Up in Singapore Towards healthy Outcomes (GUSTO) cohort study. Am J Clin Nutr 2016;104(5):1416–23.27733407
12 Colon-Ramos U, Racette SB, Ganiban J, Nguyen TG, Kocak M, Carroll KN, Volgyi E, Tylavsky FA. Association between dietary patterns during pregnancy and birth size measures in a diverse population in Southern US. Nutrients 2015;7(2):1318–32.25690420
13 Knudsen VK, Orozova-Bekkevold IM, Mikkelsen TB, Wolff S, Olsen SF. Major dietary patterns in pregnancy and fetal growth. Eur J Clin Nutr 2008;62(4):463–70.17392696
14 Lu MS, Chen QZ, He JR, Wei XL, Lu JH, Li SH, Wen XX, Chan FF, Chen NN, Qiu L, . Maternal Dietary Patterns and Fetal Growth: A Large Prospective Cohort Study in China. Nutrients 2016;8(5).
15 Northstone K, Ness AR, Emmett PM, Rogers IS. Adjusting for energy intake in dietary pattern investigations using principal components analysis. Eur J Clin Nutr 2008;62(7):931–8.17522611
16 Okubo H, Miyake Y, Sasaki S, Tanaka K, Murakami K, Hirota Y, Osaka M, Child Health Study G, Kanzaki H, Kitada M, . Maternal dietary patterns in pregnancy and fetal growth in Japan: the Osaka Maternal and Child Health Study. Br J Nutr 2012;107(10):1526–33.21929833
17 Xie Y, Madkour AS, Harville EW. Preconception Nutrition, Physical Activity, and Birth Outcomes in Adolescent Girls. J Pediatr Adolesc Gynecol 2015;28(6):471–6.26233291
18 Kennedy ET. A prenatal screening system for use in a community-based setting. J Am Diet Assoc 1986;86(10):1372–5.3760428
19 Monteagudo C, Mariscal-Arcas M, Heras-Gonzalez L, Ibanez-Peinado D, Rivas A, Olea-Serrano F. Effects of maternal diet and environmental exposure to organochlorine pesticides on newborn weight in Southern Spain. Chemosphere 2016;156:135–42.27174826
20 Grieger JA, Grzeskowiak LE, Clifton VL. Preconception dietary patterns in human pregnancies are associated with preterm delivery. J Nutr 2014;144(7):1075–80.24790026
21 Clapp JF. Diet, exercise, and feto-placental growth. Archives of Gynecology and Obstetrics 1997;260(1–4):101–8.

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the project, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. This is the analytic framework for the systematic review conducted to examine the relationship between dietary patterns before and during pregnancy and gestational age- and sex-specific birth weight.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts all contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on the relationship between dietary patterns before and during pregnancy and gestational age- and sex-specific birth weight. For this systematic review, the target population considered was women who are pregnant or able to become pregnant, ages 15-44 years. The interventions or exposures considered were dietary patterns before and during pregnancy and their comparators were different levels of adherence to a dietary pattern and/or adherence to a different dietary pattern. The confounders The outcome considered was age- and sex-specific birth weight with intermediate outcomes of fetal growth and growth velocities, IUGR, and uterine artery or umbilical cord artery Doppler measurement. The key confounders were parity, educational attainment, smoking status, race/ethnicity, maternal age, family poverty income ratio, pre-pregnancy BMI, mean total energy intake, and hypertensive disorders of pregnancy.

## SEARCH PLAN AND RESULTS

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review question: what is the relationship between dietary patterns before and during pregnancy and gestational age- and sex-adjusted birth weight. The inclusion and exclusion criteria are a set of characteristics to determine which studies will be included or excluded in the systematic review.

Table 7 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study Design | - Randomized controlled trials; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Non-randomized controlled trials; - Cross-sectional studies; - Case-control studies; - Uncontrolled studies; - Pre/post studies with a control; - Pre/post studies without a control; - Narrative reviews; - Systematic reviews; - Meta-analyses
Exposure/Intervention | - Studies that provide a description of the dietary pattern(s) (i.e., foods and beverages) consumed by subjects and that methodologically use:; ○ Indices & scores; ○ Cluster or factor analysis; ○ Reduced rank regression; ○ Other methods | - Studies that [underlined: do not] provide a description of the dietary pattern(s) (i.e., foods and beverages) consumed by subjects^41^
Comparator | - Different levels of adherence to a dietary pattern; - Adherence to a different dietary pattern
Date Range | - Studies published in the following date range: 1980-present (search date)
Language | - Studies published in English | - Studies published in languages other than English
Study Setting | - Studies conducted in Very High and High Human Development Countries*; *Determined using the most recent Human Development Index | - Studies conducted in Medium and Low Human Development Countries*; *Determined using the most recent Human Development Index
Study Duration | - Studies regardless of length
Temporality | - Studies when the exposure was assessed prior to the outcome | - Studies when the outcome was assessed prior to the exposure
Publication Status | - Studies published in peer-reviewed journals | - Grey literature, including unpublished data, manuscripts, reports, abstracts, conference proceedings
Study Subjects | - Human subjects; - Adolescent girls and women capable of becoming pregnant (15-44 years); - Pregnant girls and women (15-44 years) – single and multiple pregnancies; - Neonates | - Animal and in vitro models; - Hospitalized patients, when hospitalization is not related to pregnancy, birth and immediate postpartum; - Pregnancies conceived ONLY using Assisted Reproductive Technologies
Size of Study Groups | - Studies regardless of group size
Health Status of Study Subjects | - Studies conducted in generally healthy women of reproductive age, including women in pre/peri-conception and pregnancy; - Studies conducted in samples with elevated chronic disease risk or pregnancy related conditions, or that enroll some subjects with a disease or with health outcome of interest such as; ○ Anemia; ○ Gestational diabetes; ○ Hypertension; ○ Preeclampsia; ○ Hypermesis Gravidarum; ○ Previous adverse outcome (e.g., preterm); ○ Obesity | - Studies that exclusively enroll subjects with chronic conditions (e.g. hypertension, diabetes) that are not related to the index pregnancy; - Studies that exclusively enroll subjects with a disease or with the health outcome of interest (intermediate or endpoint health outcomes); - Studies done in hospitalized or malnourished subjects, if hospitalization is not related to index pregnancy
Outcomes | - Gestational age- and sex-specific birth weight; - Intermediate Outcomes:; ○ Fetal growth and growth velocities; ○ Intrauterine growth restriction (IUGR); ○ Uterine artery or umbilical cord artery Doppler measurement

### Search terms and electronic databases used

#### PubMed, US National Library of Medicine

- Date(s) searched: January 1980 to January 2017
- Search Terms:
  pregnancy[mh] OR “Prenatal Exposure Delayed Effects”[mesh] OR “Maternal Exposure”[mesh] OR “pregnant women”[mh] OR pregnan*[tiab] OR prenatal[tiab] OR maternal OR mother* OR postpartum OR newborn*[tiab] OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR “Infant, Newborn”[Mesh] OR neonat*[tiab] OR newly born* OR “Peripartum Period”[Mesh] OR peripartum[tiab] OR peri-partum[tiab] OR gestation* OR natal OR puerperium[tiab] OR “Maternal Nutritional Physiological Phenomena”[Mesh]
  AND
  hypertensi*[tiab] OR “Hypertension”[Mesh:NoExp] OR vomit* OR diabetes*[tiab] OR diabetic*[tiab] OR “Birth Weight”[Mesh] OR “Birth Weight”[tiab] OR “Glucose Intolerance”[Mesh] OR Glucose Intoleran*[tiab] OR glucose toleran* OR “Insulin Resistance”[Mesh] OR Insulin Resistan*[tiab] OR Dysglycemia[tiab] OR fasting blood glucose* OR “Hemoglobin A, Glycosylated”[Mesh] OR “Proteinuria”[Mesh:noexp] OR Albuminuria OR “Blood Pressure”[mh] OR “blood pressure”[tiab]
  OR
  “Diabetes, Gestational”[Mesh] OR (gestation*[tiab] AND (diabetes*[tiab] OR diabetic*[tiab])) OR “Pre-Eclampsia”[Mesh] OR “Pre-Eclampsia”[tiab] OR preeclampsia[tiab] OR “Hypertension, Pregnancy-Induced”[Mesh] OR Eclampsia OR “Gestational Age”[Mesh] OR “Morning Sickness”[Mesh] OR (Hyperemesis Gravidarum) OR “Gestational Age”[tiab] OR “Obstetric Labor, Premature”[Mesh] OR ((prematur*[tiab] OR preterm [tiab]) AND (baby[tiab] OR infant*[tiab] OR birth OR labor OR membrane* OR babies)) OR “Fetal Growth Retardation”[Mesh] OR IUGR[tiab] OR “Intrauterine growth restriction” OR “Fetal Development”[Mesh:noexp] OR “Fetal Weight”[Mesh] OR “Umbilical Arteries”[Mesh] OR “Uterine Artery”[Mesh]
  AND
  (“diet quality” OR dietary pattern* OR diet pattern* OR eating pattern* OR food pattern* OR eating habit* OR dietary habit* OR food habit* OR dietary profile* OR food profile* OR diet profile* OR eating profile* OR dietary guideline* OR dietary recommendation* OR eating style*) OR
  (DASH[ti] OR DASH[tw] OR (“dietary approaches”[ti] AND hypertension[ti]) OR “Diet, Mediterranean”[Mesh] OR Mediterranean[ti] OR vegan* OR vegetarian* OR “Diet, Vegetarian”[Mesh] OR “prudent diet” OR “western diet” OR nordiet OR omni[ti] OR omniheart[tiab] OR (Optimal Macronutrient Intake Trial to Prevent Heart Disease) OR adventist* OR ((Okinawa* OR “Ethnic Groups”[Mesh] OR “plant based” OR Mediterranean[tiab] OR Nordic[tiab] OR “heart healthy”[tiab] OR indo-mediterranean) AND (diet[mh] OR diet[tiab] OR diets[tiab] OR food[mh]))) OR
  (“Guideline Adherence”[Mesh] AND (diet OR food OR eating OR eat OR dietary OR feeding OR nutrition OR nutrient*)) OR (adherence AND (nutrient* OR nutrition OR diet OR dietary OR food OR eat OR eating) AND (guideline* OR guidance OR recommendation*)) OR
  (dietary score* OR adequacy index* OR kidmed OR Diet Quality Index* OR Food Score* OR Diet Score* OR MedDietScore OR Dietary Pattern Score* OR “healthy eating index”) OR
  ((index*[ti] OR score*[ti] OR indexes OR scoring[ti] OR indices[ti]) AND (dietary[ti] OR nutrient*[ti] OR eating[tiab] OR food[ti] OR food[mh] OR diet[ti] OR diet[mh]) AND (pattern* OR habit* OR profile*)) OR meals[mh] OR meals[tiab] OR meal[tiab] OR mealtime*[tiab]
  OR
  diet[mh:noexp] OR diet[ti] OR diets[ti] OR food*[tiab] OR “Food”[mh:noexp] OR “Eating”[mh] OR dietary intake*[tiab] OR food intake*[tiab] OR food habits[mh] OR diet habit*[tiab] OR eating habit*[tiab] OR food choice*[tiab] OR dietary choice*[tiab] OR dietary change*[tiab] NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic[sb])

#### Embase, Elsevier

- Date(s) searched: January 1980 to January 2017
- Search Terms:
  ‘pregnancy’/exp OR ‘pregnant woman’/exp OR ‘prenatal period’/exp OR ‘mother’/exp OR ‘prenatal exposure’/exp OR ‘prenatal growth’/exp OR ‘puerperium’/exp OR ‘newborn’/exp OR prematurity/exp OR pregnan*:ti,ab OR maternal:ti,ab OR mother*:ti,ab OR prenatal:ti,ab OR pre-natal:ti,ab OR ‘puerperium’:ti,ab OR postpartum:ti,ab OR newborn:ti,ab OR neonat*:ti,ab OR “newly born”:ti,ab OR periconception:ti,ab OR peri-conception:ti,ab OR pre-conception:ti,ab OR preconception;ti,ab OR gestation* OR peripartum:ti,ab OR peri-partum:ti,ab OR natal:ti,ab OR gestation* OR ‘perinatal development’/exp OR ‘perinatal care’/de OR perinatal:ti,ab OR peri-natal:ti,ab OR ‘puerperium’/de OR ‘puerperium’:ti,ab OR ‘maternal nutrition’/exp
  AND
  hypertensi* OR hyperemesis:ti,ab OR vomit*:ti,ab OR diabet* OR ‘birth weight’/exp OR birthweight:ti,ab OR ((neonatal OR newborn) NEAR/3 weight)
  OR
  ‘glucose intolerance’/exp OR (Glucose NEAR/2 Intoleran*) OR (glucose NEAR/2 toleran*) OR ‘insulin resistance’/exp OR (Insulin NEAR/1 Resistan*):ti,ab OR Dysglycemia OR “fasting blood glucose” OR ‘hemoglobin A1c’/exp OR ‘hemoglobin A1c’ OR ‘proteinuria’/exp OR albuminuria OR “Blood Pressure”/de
  OR
  ‘pregnancy diabetes mellitus’/exp OR “diabetes mellitus gravidarum”:ti,ab OR ‘eclampsia OR preeclampsia’/exp OR eclampsia:ti,ab OR preeclampsia:ti,ab OR pre-eclampsia:ti,ab OR ‘maternal hypertension’/exp OR ‘gestational age’/exp OR ‘small for date infant’/exp OR ‘gestational age’ OR ‘hyperemesis gravidarum’/exp OR ‘morning sickness’/exp OR (gestation* NEAR/2 diabet*):ti,ab OR (Obstetric NEAR/3 (Labor OR labour)) OR (labor/exp AND obstetric*) OR ‘prematurity’/exp OR ((prematur* OR preterm) NEAR/3 (baby OR infant* OR babies OR birth OR childbirth OR labor OR membrane*)) OR ‘intrauterine growth retardation’/de OR IUGR:ti,ab OR “Intrauterine growth restriction” OR ‘fetus growth’/exp OR ‘fetus development’/exp OR ‘fetus weight’/exp OR ‘umbilical artery’/exp OR ‘uterine artery’/exp OR ((fetal OR fetus OR foetal OR foetus OR embryo*) NEAR/3 (weight OR develop* OR growth)):ti,ab
  AND
  ‘eating habit’/exp OR ‘Mediterranean diet’/exp OR nordiet:ti,ab OR ‘nordic diet’:ti,ab OR DASH:ti,ab OR ‘dietary approaches to stop hypertension’:ti,ab OR vegan*:ab,ti OR vegetarian*:ab,ti OR ‘vegetarian diet’/exp OR ‘vegetarian’/exp OR ‘prudent diet’:ti,ab OR ‘western diet’:ti,ab OR ‘Western diet’/exp OR meal/de OR omniheart:ti,ab OR omni:ti OR ‘plant based diet’ OR ((eating OR food OR diet* OR calori*) NEAR/3 (pattern? OR habit? OR profile? OR recommendation? OR guideline? OR style* OR choice* OR intake OR quality)) OR ((‘ethnic, racial and religious groups’/exp OR Okinawa* OR adventist* OR ‘mediterranean’) AND (diet/exp OR eating/exp OR ‘food intake’/de OR calori* OR diet* OR food OR eating))
  OR
  Diet/de OR ‘dietary intake’/de OR ‘food preference’/de OR ‘food intake’/de OR ‘diet restriction’/exp OR ‘eating habit’/exp OR diet*:ti OR kidmed:ab,ti OR ‘meddietscore’:ab,ti OR ‘healthy eating index’:ab,ti OR ((index OR score OR scoring OR indices) NEAR/3 (diet* OR eating OR food)) OR “food consumption”
  OR
  food*:ti,ab OR “Food”/de OR Eating:ti,ab OR (dietary NEAR/1 change*):ti,ab OR Meal*:ti,ab

#### Cochrane Central Register of Controlled Trials, John Wiley & Sons

- Date(s) searched: January 1980 to January 2017
- Search Terms:
  [mh pregnancy] OR [mh “Maternal Exposure”] OR [mh “Prenatal Exposure Delayed Effects”] OR [mh “pregnant women”] OR pregnan*:ti,ab OR prenatal OR maternal OR mother* OR postpartum OR newborn*:ti,ab OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR [mh “Infant, Newborn”] OR neonat*:ti,ab OR (newly NEAR/1 born*) OR gestation* OR peripartum OR peri-partum OR natal:ti,ab OR puerperium OR gravidarum OR [mh “Peripartum Period”] OR peripartum:ti,ab OR peri-partum:ti,ab OR natal OR puerperium:ti,ab OR [mh “Maternal Nutritional Physiological Phenomena”]
  AND
  (hypertensi*:ti,ab OR [mh ^Hypertension] OR vomit*:ti,ab OR diabet*:ti,ab OR [mh “Birth Weight”] OR “Birth Weight”:ti,ab OR [mh “Glucose Intolerance”] OR (Glucose NEAR/1 Intoleran*) OR (glucose NEAR/1 toleran*) OR [mh “Insulin Resistance”] OR (Insulin NEAR/1 Resistan*:ti,ab) OR Dysglycemia:ti,ab OR “fasting blood glucose” OR [mh “Hemoglobin A, Glycosylated”] OR [mh ^“Proteinuria”] OR Albuminuria OR [mh “Blood Pressure”] OR “blood pressure”:ti,ab)
  OR
  [mh “Diabetes, Gestational”] OR (gestation* NEAR/1 diabet*) OR [mh “Pre-Eclampsia”] OR “Pre-Eclampsia”:ti,ab OR preeclampsia:ti,ab OR [mh “Hypertension, Pregnancy-Induced”] OR Eclampsia OR [mh “Gestational Age”] OR [mh “Morning Sickness”] OR (Hyperemesis NEAR/3 Gravidarum) OR “Gestational Age”:ti,ab OR [mh “Birth Weight”] OR “Birth Weight”:ti,ab OR ((neonatal OR newborn) NEAR/3 weight) OR [mh “Obstetric Labor, Premature”] OR ((prematur*:ti,ab OR preterm:ti,ab) AND (baby:ti,ab OR infant*:ti,ab OR birth OR labor OR membrane* OR babies)) OR [mh “Fetal Growth Retardation”] OR IUGR:ti,ab OR “Intrauterine growth restriction” OR [mh ^“Fetal Development”] OR [mh “Fetal Weight”] OR [mh “Umbilical Arteries”] OR [mh “Uterine Artery”]
  AND (diet:ti OR diets:ti OR dietary:ti OR meal*:ti,ab OR “prudent diet” OR nordiet:ti,ab OR omniheart OR “Optimal Macronutrient Intake Trial to Prevent Heart Disease” OR ((Index OR score OR indices OR scoring) NEAR/3 (dietary OR diet OR food OR eating)) OR “adequacy index” OR kidmed OR MedDietScore)
  OR ‘dietary approaches to stop hypertension’:ti,ab OR omniheart:ti,ab OR omni:ti OR ‘plant based diet’ OR ((eating OR food OR diet* OR calori*) NEAR/3 (pattern? OR habit? OR profile? OR recommendation? OR guideline? OR style* OR choice* OR intake OR quality))
  OR
  food*:ti,ab OR Eating:ti,ab OR (dietary NEAR/1 change*):ti,ab OR DASH:ti,ab OR vegan*:ab,ti OR vegetarian*:ab,ti OR omni:ti OR ((ethni* OR racial OR religio* OR asia* OR western OR Okinawa* OR adventist* OR ‘mediterranean’ OR Nordic* OR indo-mediterranean) NEAR/3 (calori* OR diet* OR food OR eating))
  OR [mh “Diet, Mediterranean”] OR [mh “Diet, Vegetarian”] OR ([mh “Ethnic Groups”] AND ([mh diet] OR diet*:ti,ab OR [mh ^food] OR eat:ti,ab OR eating:ti,ab OR [mh “Eating”] OR [mh “food habits”])) OR
  ([mh “Guideline Adherence”] AND (diet OR food OR eating OR eat OR dietary)) OR ((adhere* OR adhering) AND (diet OR dietary OR food OR eat OR eating) AND (guideline* OR guidance OR recommendation*)) OR
  [mh meals] OR [mh ^diet] OR diet*:ti,ab OR [mh ^“Food”] OR [mh “Eating”] OR [mh “food habits”]

#### CINAHL (Plus) with Full Text, EBSCO (Cumulative Index to Nursing and Allied Health Literature)

- Date(s) searched: January 1980 to January 2017
- Search Terms:
  (MH “Food and Beverages”) OR (MH “Food”) OR (MH “Diet”) OR (MH “Eating”) OR (MH “Eating Behavior”) OR (MH “Meals+”) OR (MH “Food Preferences”) OR (MH “Food Habits”) OR (MH “Mediterranean Diet”) OR (MH “Diet, Western”) OR (MH “DASH Diet”) OR (MH “Vegetarianism”)
  OR meal* OR “prudent diet” OR nordiet OR omniheart OR “Optimal Macronutrient Intake Trial to Prevent Heart Disease” OR ((Index OR score OR indices OR scoring) N3 (dietary OR diet OR food OR eating)) OR “adequacy index” OR kidmed OR MedDietScore
  OR “dietary approaches to stop hypertension” OR “plant based diet” OR ((eating OR food* OR diet* OR calori*) N3 (pattern? OR habit? OR profile? OR recommendation? OR guideline? OR style* OR choice* OR intake OR quality))
  OR
  (dietary NEAR/1 change*) OR vegan* OR vegetarian* OR ((ethni* OR racial OR religio* OR asia* OR western OR Okinawa* OR adventist* OR ‘mediterranean’ OR Nordic* OR indo-mediterranean OR omni*) N3 (calori* OR diet* OR food OR eating))
  OR (MH “Ethnic Groups+”) AND ((mh diet) OR diet* OR (MH food) OR eat OR eating OR (MH “Eating”) OR MH “food habits”)) OR
  ((adhere* OR adhering) N3 (diet OR dietary OR food OR eat OR eating)) AND (guideline* OR guidance OR recommendation*))
  (MH “Maternal Nutritional Physiology+”) OR (MH “Maternal Exposure”) OR (MH “Pregnancy+”) OR (MH “Pregnancy in Adolescence+”) OR (MH “Maternal Age 14 and Under”) OR (MH “Pregnancy Outcomes”) OR (MH “Mothers+”) OR (MH “Prenatal Nutritional Physiology”) OR (MH “Infant, Newborn+”) OR (MH “Postnatal Period+”) OR (MH “Periconceptual Period”)
  AND
  (MH “Hypertension+”) OR (MH “Nausea and Vomiting+”) OR (MH “Vomiting+”) OR (MH “Birth Weight”) OR (MH “Glucose Tolerance Test”) OR (MH “Prediabetic State”) OR (MH “Glucose Intolerance”) OR (MH “Insulin Resistance+”) OR (MH “Blood Pressure+”) OR (MH “Proteinuria+”) OR (MH “Hemoglobin A, Glycosylated”)
  OR
  (MH “Diabetes Mellitus, Gestational”) OR (MH “Gestational Age”) OR (MH “Pre-Eclampsia+”) OR (MH “Eclampsia+”) OR (MH “Fetal Growth Retardation”) OR (MH “Fetal Weight”) OR (MH “Umbilical Arteries”) OR (MH “Delivery, Obstetric+”)
  Limiters - Published Date: 19800101-; Peer Reviewed; English Language;
  Exclude MEDLINE records; Pregnancy
  Narrow by SubjectMajor: - energy intake
  Narrow by SubjectMajor: - vegetarianism
  Narrow by SubjectMajor: - women’s health
  Narrow by SubjectMajor: - pregnancy outcomes
  Narrow by SubjectMajor: - pregnancy complications
  Narrow by SubjectMajor: - food habits
  Narrow by SubjectMajor: - diabetes mellitus, gestational

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between dietary patterns before and during pregnancy and gestational age- and sex-adjusted birth weight. The literature search yielded 9103 articles. During title and abstract screening 8725 articles were screened out. During full-text screening, 337 articles were screened out. During the hand search, 0 additional articles were identified to include. 21 articles total were included in this systematic review at the end of the search and screening process.

This flow chart illustrates the literature search and screening results for articles examining the relationship between dietary patterns before and during pregnancy and gestational age- and sex-specific birth weight. The results of the electronic database searches were screened independently by two NESR analysts in a step-wise manner by reviewing titles, abstracts, and full text articles to determine which articles met the criteria for inclusion. A manual search was done to ascertain articles not identified through the electronic database search. The systematic review on the relationship between dietary patterns before and during pregnancy and gestational age- and sex-specific birth weight included 21 articles. The literature search was conducted for multiple systematic reviews that addressed the relationships between dietary patterns before and during pregnancy on gestational age- and sex-specific birth weight, hypertensive disorders of pregnancy, gestational diabetes mellitus, and gestational age at birth; the systematic reviews on hypertensive disorders of pregnancy, gestational diabetes mellitus, and gestational age at birth are reported elsewhere.

#### List of excluded articles

The table below lists the excluded articles with at least one reason for exclusion, but may not reflect all possible reasons.

Table 8 List of excluded articles

| Excluded Citations | Reasons for Exclusion
1 | Aaltonen, J, Ojala, T, Laitinen, K et al. Risk Reduction of Infant Insulin Resistance by Dietary Intervention during Pregnancy and Breastfeeding. Pediatric Academic Societies Annual Meeting; 2009 May 2 5; Baltimore MD, United States, 2009 | Dependent variable
2 | Abel, Ht, Bannert, N, Starke, I et al. Study into Ca/P homeostasis in premature babies on different diets. Klin Padiatr, 1991, 203 | Independent variable
3 | Adami, G. F., Friedman, D., Cuneo, S. et al. Intravenous nutritional support in pregnancy. Experience following biliopancreatic diversion. Clinical Nutrition, 1992, 11: 106-109 | Independent variable
4 | Akbari, Z., Mansourian, M., Kelishadi, R. Relationship of the intake of different food groups by pregnant mothers with the birth weight and gestational age: Need for public and individual educational programs. J Educ Health Promot, 2015, 4. PMID:25883993. | Independent variable
5 | Alfonso, H. Preventing preeclampsia: the evidence on nutrients. Nurs Womens Health, 2009, 13: 419-21. PMID:19821918. | Study design
6 | Ali, H. I., Jarrar, A. H., El Sadig, M. et al. Diet and carbohydrate food knowledge of multi-ethnic women: a comparative analysis of pregnant women with and without Gestational Diabetes Mellitus. PLoS One, 2013, 8. PMID:24069200. | Study design
7 | Alwan, N. A., Greenwood, D. C., Simpson, N. A. et al. Dietary iron intake during early pregnancy and birth outcomes in a cohort of British women. Hum Reprod, 2011, 26: 911-9. PMID:21303776. | Independent variable
8 | Andreasyan, K., Ponsonby, A. L., Dwyer, T. et al. Higher maternal dietary protein intake in late pregnancy is associated with a lower infant ponderal index at birth. Eur J Clin Nutr, 2007, 61: 498-508. PMID:17136041. | Independent variable
9 | Arkkola, T., Uusitalo, U., Kronberg-Kippila, C. et al. Seven distinct dietary patterns identified among pregnant Finnish women--associations with nutrient intake and sociodemographic factors. Public Health Nutr, 2008, 11: 176-82. PMID:17610760. | Dependent variable
10 | Asaka, A., Imaizumi, Y., Inouye, E. Analysis of multiple births in Japan. V. Effects of gestational age, maternal age and other factors on growth rate of weight in twins. Jinrui Idengaku Zasshi, 1981, 26: 83-90. PMID:7328851. | Independent variable
11 | Asbee, Sm, Jenkins, Tr, Butler, Jr et al. Dietary counseling prevents excessive weight gain during pregnancy, a randomized controlled trial. Obstet Gynecol, 2008, 111 | Dependent variable
12 | Asp, N. G. Nutrition and human development. Scandinavian Journal of Food and Nutrition, 2006, 50 | Independent variable, study design
13 | Babson, Sg, Bramhall, Jl. Diet and growth in the premature infant. Journal of Pediatrics, 1969, 74: 890-900 | Date
14 | Bakouei, S., Reisian, F., Lamyian, M. et al. High Intake of Manganese During Second Trimester, Increases the Risk of Preterm Delivery: A Large Scale Cohort Study. Glob J Health Sci, 2015, 7: 226-32. PMID:26156900. | Independent variable
15 | Bao, W., Bowers, K., Tobias, D. K. et al. Prepregnancy low-carbohydrate dietary pattern and risk of gestational diabetes mellitus: a prospective cohort study. Am J Clin Nutr, 2014, 99: 1378-84. PMID:24717341. | Independent variable
16 | Bao, W., Li, S., Chavarro, J. E. et al. Low Carbohydrate-Diet Scores and Long-term Risk of Type 2 Diabetes Among Women With a History of Gestational Diabetes Mellitus: A Prospective Cohort Study. Diabetes Care, 2016, 39: 43-9. PMID:26577416. | Dependent variable
17 | Bao, W., Tobias, D. K., Hu, F. B. et al. Pre-pregnancy potato consumption and risk of gestational diabetes mellitus: prospective cohort study. Bmj, 2016, 352. PMID:26759275. | Independent variable
18 | Bao, W., Tobias, D. K., Olsen, S. F. et al. Pre-pregnancy fried food consumption and the risk of gestational diabetes mellitus: a prospective cohort study. Diabetologia, 2014, 57: 2485-91. PMID:25303998. | Independent variable
19 | Baron, R., Te Velde, S. J., Heymans, M. W. et al. The Relationships of Health Behaviour and Psychological Characteristics with Spontaneous Preterm Birth in Nulliparous Women. Matern Child Health J, 2016, . PMID:27581004. | Independent variable
20 | Bell, E. H., Geyer, J., Jones, L. A structured intervention improves breastfeeding success for ill or preterm infants. MCN Am J Matern Child Nurs, 1995, 20: 309-14. PMID:8551932. | Dependent variable
21 | Berntorp, K. E. Gestational diabetes: what’s up?. Diabetologia, 2016, 59: 1382-1384 | Study design
22 | Bertolotto, A., Volpe, L., Calianno, A. et al. Physical activity and dietary habits during pregnancy: effects on glucose tolerance. J Matern Fetal Neonatal Med, 2010, 23: 1310-4. PMID:20334531. | Independent variable, study design
23 | Bhatia, B. D., Banerjee, D., Agarwal, D. K. et al. Fetal growth: relationship with maternal dietary intakes. Indian J Pediatr, 1983, 50: 113-20. PMID:6618569. | Country
24 | Bjerregaard, P., Hansen, J. C. Effects of smoking and marine diet on birthweight in Greenland. Arctic Med Res, 1996, 55: 156-64. PMID:9115541. | Independent variable
25 | Bloomfield, F. H., Oliver, M. H., Hawkins, P. et al. A periconceptional nutritional origin for noninfectious preterm birth. Science, 2003, 300. PMID:12714735. | Independent variable, health status
26 | Bo, S., Rosato, R., Ciccone, G. et al. Simple lifestyle recommendations and the outcomes of gestational diabetes. A 2 − 2 factorial randomized trial. Diabetes Obes Metab, 2014, 16: 1032-5. PMID:24646172. | Independent variable, health status
27 | Bobinski, R., Mikulska, M., Mojska, H. et al. Assessment of the diet components of pregnant women as predictors of risk of preterm birth and born baby with low birth weight. Ginekol Pol, 2015, 86: 292-9. PMID:26117989. | Independent variable, study design
28 | Bobinski, R., Mikulska, M., Mojska, H. et al. The Dietary Composition of Women Who Delivered Healthy Full-Term Infants, Preterm Infants, and Full-Term Infants Who Were Small for Gestational Age. Biol Res Nurs, 2015, 17: 495-502. PMID:25358685. | Independent variable, study design
29 | Borberg, C., Gillmer, M. D., Brunner, E. J. et al. Obesity in pregnancy: the effect of dietary advice. Diabetes Care, 1980, 3: 476-81. PMID:6993162. | Independent variable
30 | Borgen, I., Aamodt, G., Harsem, N. et al. Maternal sugar consumption and risk of preeclampsia in nulliparous Norwegian women. Eur J Clin Nutr, 2012, 66: 920-5. PMID:22713766. | Independent variable
31 | Bower, D. The influence of dietary salt intake on pre-eclampsia. Journal of obstetrics and gynaecology of the British Commonwealth, 1961, 63: 123-6 | Date
32 | Bowers, K., Tobias, D. K., Yeung, E. et al. A prospective study of prepregnancy dietary fat intake and risk of gestational diabetes. Am J Clin Nutr, 2012, 95: 446-53. PMID:22218158. | Independent variable
33 | BrantsÃ¦ter, A. L., Haugen, M., Myhre, R. et al. Diet matters, particularly in pregnancy – Results from MoBa studies of maternal diet and pregnancy outcomes. Norsk Epidemiologi, 2014, 24: 63-77 | Study design
34 | Brantsaeter, A. L., Myhre, R., Haugen, M. et al. Intake of probiotic food and risk of preeclampsia in primiparous women: the Norwegian Mother and Child Cohort Study. Am J Epidemiol, 2011, 174: 807-15. PMID:21821542. | Independent variable
35 | Breslow, S, Belafsky, Ha, Shangold, Je et al. Control of weight gain in pregnancy: double blind study of a dieting aid. Clinical medicine, 1963, 70: 931-8 | Date
36 | Brooke, O. G. Low birth weight babies. Nutrition and feeding. Br J Hosp Med, 1982, 28: 462-9. PMID:7171896. | Dependent variable
37 | Brooke, O. G. Nutrition in the preterm infant. Lancet, 1983, 1: 514-6. PMID:6131220. | Study subjects
38 | Brown, J. E., Kahn, E. S., Hartman, T. J. Profet, profits, and proof: do nausea and vomiting of early pregnancy protect women from harmful vegetables?. Am J Obstet Gynecol, 1997, 176: 179-81. PMID:9024110. | Independent variable
39 | Brumfield, C. G., Huddleston, J. F. The management of diabetic ketoacidosis in pregnancy. Clin Obstet Gynecol, 1984, 27: 50-9. PMID:6423330. | Independent variable
40 | Bruno, R., Petrella, E., Bertarini, V. et al. Adherence to a lifestyle programme in overweight/obese pregnant women and effect on gestational diabetes mellitus: a randomized controlled trial. Matern Child Nutr, 2016, . PMID:27647837. | Independent variable, study design
41 | Buchanan, T. A., Kjos, S. L. Diabetes and pregnancy. Curr Ther Endocrinol Metab, 1994, 5: 278-83. PMID:7704732. | Study design
42 | Buul, E, Rijpkema, A, Steegers, E et al. Chronic dietary sodium restriction in pregnancy reduces calcium intake. J Perinat Med, 1992, 20 | Independent variable
43 | Campbell, Dm. Dietary restriction in obesity and its effect on neonatal outcome. Nutrition in Pregnancy. Proceedings of 10th Study Group of the Rcog; 1983; London, UK, 1983, : 243-50 | Not peer-reviewed
44 | Canda, M. T., Sezer, O., Demir, N. An audit of seafood consumption awareness during pregnancy and its association with maternal and fetal outcomes in a Turkish population. J Obstet Gynaecol, 2011, 31: 293-7. PMID:21534748. | Independent variable
45 | Carmichael, S. L., Yang, W., Shaw, G. M. Maternal dietary nutrient intake and risk of preterm delivery. Am J Perinatol, 2013, 30: 579-88. PMID:23208764. | Independent variable, study design
46 | Carter, J. P., Furman, T., Hutcheson, H. R. Preeclampsia and reproductive performance in a community of vegans. South Med J, 1987, 80: 692-7. PMID:3589760. | Independent variable
47 | Carver, Jd, Saste, Md, Sosa, R et al. Dietary nucleotide (NT) effects on superior mesenteric artery (SMA) blood flow in preterm infants. Pediatr Res, 2000, 47 | Independent variable
48 | C’De Baca, J., Lapham, S. C., Skipper, B. J. et al. Use of computer interview data to test associations between risk factors and pregnancy outcomes. Comput Biomed Res, 1997, 30: 232-43. PMID:9281330. | Independent variable
49 | Chamberlain, G. Epidemiology and aetiology of the preterm baby. Clin Obstet Gynaecol, 1984, 11: 297-314. PMID:6478726. | Study design
50 | Chandler-Laney, P. C., Schneider, C. R., Gower, B. A. et al. Association of late-night carbohydrate intake with glucose tolerance among pregnant African American women. Matern Child Nutr, 2016, 12: 688-98. PMID:25786515. | Independent variable
51 | Chavarro, J. E., Halldorsson, T. I., Leth, T. et al. A prospective study of trans fat intake and risk of preeclampsia in Denmark. Eur J Clin Nutr, 2011, 65: 944-51. PMID:21559043. | Independent variable
52 | Chen, C. M., Weng, H. C., Li, Y. C. et al. The evaluation of dietary intervention on the blood glucose level of gestational diabetes mellitus pregnant women. Nutritional Sciences Journal, 1999, 24: 250-261 | Language
53 | Chen, L., Hu, F. B., Yeung, E. et al. Prospective study of pre-gravid sugar-sweetened beverage consumption and the risk of gestational diabetes mellitus. Diabetes Care, 2009, 32: 2236-41. PMID:19940226. | Independent variable
54 | Chong, M. F., Chia, A. R., Colega, M. et al. Maternal Protein Intake during Pregnancy Is Not Associated with Offspring Birth Weight in a Multiethnic Asian Population. J Nutr, 2015, 145: 1303-10. PMID:25948786. | Independent variable
55 | Christian, K, Andreas, M, Martin, F. Diet and lifestyle modification in mothers with burnout syndrome: Ayurvedic versus conventional standard counselling-design of a randomised clinical pilot study (VEDA-Trial) [abstract]. European journal of integrative medicine [abstracts of the 5th european congress for integrative medicine; 2012 sept 21-22; flo, 2012, 4: 47-8 | Dependent variable
56 | Clapp, J. F. Effects of Diet and Exercise on Insulin Resistance during Pregnancy. Metab Syndr Relat Disord, 2006, 4: 84-90. PMID:18370754. | Study design
57 | Clausen, T., Slott, M., Solvoll, K. et al. High intake of energy, sucrose, and polyunsaturated fatty acids is associated with increased risk of preeclampsia. Am J Obstet Gynecol, 2001, 185: 451-8. PMID:11518908. | Independent variable
58 | Coelho Nde, L., Cunha, D. B., Esteves, A. P. et al. Dietary patterns in pregnancy and birth weight. Rev Saude Publica, 2015, 49. PMID:26398873. | Study design
59 | Cooney, G. Food for thought. Midwives, 2008, 11: 30-1. PMID:24902215. | Study design
60 | Cooper, M. L. Stories to learn from: toxemia in pregnancy. Midwifery Today Int Midwife, 2014, : 18-21. PMID:25980103. | Not peer-reviewed
61 | Corbett, M. A., Burst, H. V. Nutritional intervention in pregnancy. J Nurse Midwifery, 1983, 28: 23-9. PMID:6554311. | Study design, independent variable
62 | Cosgrove, M., Davies, D. P. Poor diet in pregnancy may be a proxy for some other hostile influence on fetal growth [8]. Br Med J, 1996, 312: 1478-1479 | Independent variable, study design
63 | Costa-Orvay, Ja, Figueras-Aloy, J, Romera, G et al. The effects of varying protein and energy intakes on the growth and body composition of very low birth weight infants. Nutr J, 2011, 10 | Independent variable
64 | Crozier, S. R., Inskip, H. M., Godfrey, K. M. et al. Nausea and vomiting in early pregnancy: Effects on food intake and diet quality. Matern Child Nutr, 2016, . PMID:27896913. | Dependent variable
65 | Dancause, K. N., Mutran, D., Elgbeili, G. et al. Dietary change mediates relationships between stress during pregnancy and infant head circumference measures: the QF2011 study. Matern Child Nutr, 2016, . PMID:27562643. | Independent variable
66 | Darling, A. M., Mitchell, A. A., Werler, M. M. Preconceptional Iron Intake and Gestational Diabetes Mellitus. Int J Environ Res Public Health, 2016, 13. PMID:27231921. | Independent variable
67 | Davidson, J. K. Newer approaches to diet management of diabetes: calorie control. Med Times, 1980, 108: 35-40. PMID:7374404. | Study design
68 | Davies, W. E., Hopkins, P. C., Rose, S. J. et al. The influence of different taurine diets on hearing development in normal babies. A preliminary report. Adv Exp Med Biol, 1996, 403: 631-7. PMID:8915404. | Independent variable
69 | Davison, J. M., Lindheimer, M. D. Pregnancy in renal transplant recipients. J Reprod Med, 1982, 27: 613-21. PMID:6757420. | Health status
70 | Dawn, Cs. Effects of substandard prenatal diet and nutrition on the development and incidence of pre-eclampsia of pregnancy. J Obstet Gynaecol India, 1961, 12: 237-45 | Date
71 | de Seymour, J., Chia, A., Colega, M. et al. Maternal Dietary Patterns and Gestational Diabetes Mellitus in a Multi-Ethnic Asian Cohort: The GUSTO Study. Nutrients, 2016, 8. PMID:27657116. | Study design
72 | Deka, D., Sharma, N. Nutrition in pregnancy and lactation. Perinatology, 2005, 7: 1-15 | Study design
73 | Delemarre, F. M., van Leest, L. A., Jongsma, H. W. et al. Effect of low-sodium diet on uteroplacental circulation. J Matern Fetal Med, 2000, 9: 197-200. PMID:11048827. | Independent variable
74 | Demmelmair, H, Klingler, M, Campoy, C et al. The influence of habitual diet and increased docosahexaenoic acid intake during pregnancy on the fatty acid composition of individual placental lipids [Study design]. J Pediatr Gastroenterol Nutr, 2005, 40: 622-3 | Study design
75 | Deveer, R., Deveer, M., Akbaba, E. et al. The effect of diet on pregnancy outcomes among pregnant with abnormal glucose challenge test. Eur Rev Med Pharmacol Sci, 2013, 17: 1258-61. PMID:23690197. | Independent variable
76 | Dieckmann, Wj, Davis, Me, Rynkiewicz, Lm et al. Does the administration of diethylstilbestrol during pregnancy have therapeutic value?. Am J Obstet Gynecol, 1953, 66: 1062-75 | Date
77 | Diet & nutrition. Good news: caffeine in pregnancy doesn’t affect the baby’s growth..and folic acid seems to prevent cleft lip. Child Health Alert, 2007, 25: 5-6. PMID:17443983. | Not peer-reviewed
78 | Dodd, J. M., Deussen, A. R., Mohamad, I. et al. The effect of antenatal lifestyle advice for women who are overweight or obese on secondary measures of neonatal body composition: The LIMIT randomised trial. BJOG: An International Journal of Obstetrics and Gynaecology, 2016, 123: 244-253 | Independent variable
79 | Dodd, J. M., McPhee, A. J., Turnbull, D. et al. The effects of antenatal dietary and lifestyle advice for women who are overweight or obese on neonatal health outcomes: the LIMIT randomised trial. BMC Med, 2014, 12. PMID:25315325. | Independent variable
80 | Dominguez, L. J., Martinez-Gonzalez, M. A., Basterra-Gortari, F. J. et al. Fast food consumption and gestational diabetes incidence in the SUN project. PLoS One, 2014, 9. PMID:25215961. | Independent variable
81 | Donnelly, J, Horan, M, Walsh, J et al. Impact of a Low GI Diet on Neonatal Body Composition [ROLO Kids]. Pediatric Academic Societies Annual Meeting, 2013, | Not peer-reviewed
82 | Donnelly, J. M., Walsh, J. M., Byrne, J. et al. Impact of maternal diet on neonatal anthropometry: a randomized controlled trial. Pediatr Obes, 2015, 10: 52-6. PMID:24443392. | Independent variable
83 | Doyle, W. Maternal nutrition and low birth weight. J Fam Health Care, 2002, 12. PMID:12630147. | Study design
84 | Doyle, W., Crawford, M. A., Wynn, A. H. A. et al. Maternal nutrient intake and birth-weight. Journal of Human Nutrition and Dietetics, 1989, 2: 415-422 | Independent variable
85 | Drake, A. J., McPherson, R. C., Godfrey, K. M. et al. An unbalanced maternal diet in pregnancy associates with offspring epigenetic changes in genes controlling glucocorticoid action and foetal growth. Clin Endocrinol (Oxf), 2012, 77: 808-15. PMID:22642564. | Dependent variable
86 | Drouillet, P., Kaminski, M., De Lauzon-Guillain, B. et al. Association between maternal seafood consumption before pregnancy and fetal growth: evidence for an association in overweight women. The EDEN mother-child cohort. Paediatr Perinat Epidemiol, 2009, 23: 76-86. PMID:19228317. | Independent variable
87 | Dubois, S., Coulombe, C., Pencharz, P. et al. Ability of the Higgins Nutrition Intervention Program to improve adolescent pregnancy outcome. J Am Diet Assoc, 1997, 97: 871-8. PMID:9259709. | Independent variable
88 | Dunn, C., Kolasa, K., Dunn, P. C. et al. Dietary intake of pregnant adolescents in a rural southern community. J Am Diet Assoc, 1994, 94: 1040-1. PMID:8071488. | Independent variable, dependent variable
89 | Ebbs, Jh, Tisdall, Ff, Scott, Wa. The influence of prenatal diet on the mother and child. Journal of Nutrition, 1941, 22: 515-26 | Date
90 | Elmacioglu, F., Surucu, B., Alper, T. et al. Is adequate and balanced nutrition during pregnancy more effective than iron and folic acid supplements?. Central European Journal of Medicine, 2010, 5: 235-242 | Dependent variable
91 | Ershoff, Dh, Aaronson, Nk, Danaher, Bg et al. Behavioral, health, and cost outcomes of an HMO based prenatal health education program. Public health reports, 1983, 98: 536-47 | Independent variable
92 | Ershoff, D. H., Aaronson, N. K., Danaher, B. G. et al.. Behavioral, health, and cost outcomes of an HMO-based prenatal health education program. Public Health Rep, 1983, 98: 536-47. PMID:6419268. | Duplicate
93 | Eshriqui, I., Vilela, A. A., Rebelo, F. et al. Gestational dietary patterns are not associated with blood pressure changes during pregnancy and early postpartum in a Brazilian prospective cohort. Eur J Nutr, 2016, 55: 21-32. PMID:25526968. | Dependent variable
94 | Fairburn, C. G., Stein, A., Jones, R. Eating habits and eating disorders during pregnancy. Psychosom Med, 1992, 54: 665-72. PMID:1454960. | Independent variable
95 | Farbu, J., Haugen, M., Meltzer, H. M. et al. Impact of singlehood during pregnancy on dietary intake and birth outcomes- a study in the Norwegian Mother and Child Cohort Study. BMC Pregnancy Childbirth, 2014, 14. PMID:25475509. | Independent variable
96 | Fard, N Mehrabian F Sarraf-Zadegan NS. Fat-modified diets during pregnancy and lactation and serum lipids after birth. Indian J Pediatr, 2004, 71: 683-7 | Country
97 | Farland, L. V., Rifas-Shiman, S. L., Gillman, M. W. Early Pregnancy Cravings, Dietary Intake, and Development of Abnormal Glucose Tolerance. J Acad Nutr Diet, 2015, 115. PMID:26099686. | Study design, independent variable
98 | Ferland, S., O’Brien, H. T. Maternal dietary intake and pregnancy outcome. J Reprod Med, 2003, 48: 86-94. PMID:12621791. | Independent variable
99 | Flynn, A. C., Seed, P. T., Patel, N. et al. Dietary patterns in obese pregnant women; influence of a behavioral intervention of diet and physical activity in the UPBEAT randomized controlled trial. Int J Behav Nutr Phys Act, 2016, 13. PMID:27894316. | Health status
100 | Ford, J. H. Preconception risk factors and SGA babies: Papilloma virus, omega 3 and fat soluble vitamin deficiencies. Early Hum Dev, 2011, 87: 785-9. PMID:21705161. | Independent variable
101 | Fowles, E. R., Gabrielson, M. First trimester predictors of diet and birth outcomes in low-income pregnant women. J Community Health Nurs, 2005, 22: 117-30. PMID:15877540. | Independent variable, study design
102 | Fraser, R. B., Ford, F. A., Milner, R. D. G. A controlled trial of a high dietary fibre intake in pregnancy-effects in plasma glucose and insulin levels. Diabetologia, 1983, 25: 238-241 | Independent variable
103 | Fraser, Rb. High fibre diets in pregnancy. Nutrition in Pregnancy. Proceedings of 10th Study Group of the Royal College of Obstetricians and Gynaecologists; 1982 September, 1983, : 269-80 | Independent variable, not peer reviewed
104 | Garratt, F. N. Pre-eclampsia: a challenge to public health teams worldwide to ensure that maternal diets contain adequate levels of folic acid, n3 polyunsaturated fatty acids and vitamin D at conception. Public Health, 2009, 123: 95-6. PMID:19058819. | Study design
105 | Gennaro, S., Biesecker, B., Fantasia, H. C. et al. Nutrition profiles of African [corrected] American women in the third trimester. MCN Am J Matern Child Nurs, 2011, 36: 120-6. PMID:21350375. | Independent variable, dependent variable
106 | Gerrard, J., Popeski, D., Ebbeling, L. et al. Dietary omega 3 fatty acids and gestational hypertension in the Inuit. Arctic Med Res, 1991, : 763-7. PMID:1365294. | Independent variable, study design
107 | Gesteiro, E., Rodriguez Bernal, B., Bastida, S. et al. Maternal diets with low healthy eating index or Mediterranean diet adherence scores are associated with high cord-blood insulin levels and insulin resistance markers at birth. Eur J Clin Nutr, 2012, 66: 1008-15. PMID:22828732. | Dependent variable
108 | Ghebremeskel, K., Leighfield, M., Ashwell, M. et al. Infant brain lipids and diet [1]. Lancet, 1992, 340: 1093-1094 | Dependent variable
109 | Gillen, L., Tapsell, L. C., Martin, G. S. et al. The type and frequency of consumption of carbohydrate-rich foods may play a role in the clinical expression of insulin resistance during pregnancy. Dietetics, 2002, 59: 135-143 | Dependent variable
110 | Glueck, C. J., Goldenberg, N., Pranikoff, J. et al. Effects of metformin-diet intervention before and throughout pregnancy on obstetric and neonatal outcomes in patients with polycystic ovary syndrome. Curr Med Res Opin, 2013, 29: 55-62. PMID:23205605. | Health status
111 | Godfrey, K., Robinson, S., Barker, D. J. et al. Maternal nutrition in early and late pregnancy in relation to placental and fetal growth. Bmj, 1996, 312: 410-4. PMID:8601112. | Independent variable
112 | Grant, S. M., Wolever, T. M., O’Connor, D. L. et al. Effect of a low glycaemic index diet on blood glucose in women with gestational hyperglycaemia. Diabetes Res Clin Pract, 2011, 91: 15-22. PMID:21094553. | Independent variable
113 | Gray-Donald, K., Robinson, E., Collier, A. et al. Intervening to reduce weight gain in pregnancy and gestational diabetes mellitus in Cree communities: an evaluation. Cmaj, 2000, 163: 1247-51. PMID:11107459. | Independent variable
114 | Grivell, R. M., Yelland, L. N., Deussen, A. et al. Antenatal dietary and lifestyle advice for women who are overweight or obese and the effect on fetal growth and adiposity: the LIMIT randomised trial. Bjog, 2016, 123: 233-43. PMID:26841216. | Independent variable
115 | Guilloty, N. I., Soto, R., Anzalota, L. et al. Diet, Pre-pregnancy BMI, and Gestational Weight Gain in Puerto Rican Women. Matern Child Health J, 2015, 19: 2453-61. PMID:26100133. | Independent variable, dependent variable
116 | Guldner, L., Monfort, C., Rouget, F. et al. Maternal fish and shellfish intake and pregnancy outcomes: a prospective cohort study in Brittany, France. Environ Health, 2007, 6. PMID:17958907. | Independent variable
117 | Gupta, A. P., Bhandari, B., Gupta, A. et al. Stool pH and sugar in preterm neonates. Indian J Pediatr, 1984, 51: 391-3. PMID:6526446. | Independent variable
118 | Haas, A. V. Diet du jour! Pregnancy and popular diets. Midwifery Today Int Midwife, 2014, : 53-5. PMID:25975083. | Study design, non peer-reviewed
119 | Haggarty, P., Campbell, D. M., Duthie, S. et al. Diet and deprivation in pregnancy. Br J Nutr, 2009, 102: 1487-97. PMID:19682400. | Independent variable
120 | Halldorsson, T. I., Thorsdottir, I., Meltzer, H. M. et al. Dioxin-like activity in plasma among Danish pregnant women: dietary predictors, birth weight and infant development. Environ Res, 2009, 109: 22-8. PMID:18945425. | Independent variable
121 | Halldorsson, T. I., Thorsdottir, I., Meltzer, H. M. et al. Linking exposure to polychlorinated biphenyls with fatty fish consumption and reduced fetal growth among Danish pregnant women: a cause for concern?. Am J Epidemiol, 2008, 168: 958-65. PMID:18718897. | Independent variable
122 | Hankin, Me, Symonds, Em. Body weight, diet and pre-eclamptic toxaemia of pregnancy. gynaecology, 1962, 4: 156-60 | Date
123 | Harper, V., MacInnes, R., Campbell, D. et al. Increased birth weight in northerly islands: is fish consumption a red herring?. Bmj, 1991, 303. PMID:1878642. | Independent variable
124 | Hatfield, Hm, Dunstan, Ja, Hayes, L et al. Dietary N-3 polyunsaturated fatty acid (PUFA) supplementation during pregnancy is associated with changes in cord blood (CB) progenitor numbers and responsiveness to IL-5 in infants at risk of atopy [Abstract]. Journal of allergy and clinical immunology, 2003, 111 | Study design
125 | Haugen, M., Brantsaeter, A. L., Trogstad, L. et al. Vitamin D supplementation and reduced risk of preeclampsia in nulliparous women. Epidemiology, 2009, 20: 720-6. PMID:19451820. | Independent variable
126 | Hayashi, Tt, Phitaksphraiwan, P, Willson, Jr. Effects of diet and diuretic agents in pregnancy toxemias. Obstet Gynecol, 1963, 22: 327-34 | Date
127 | Healthy diet halves the risk of diabetes after pregnancy. Kidney Care, 2013, 10: 6-6 | Dependent variable
128 | Hegsted, D. M. What is a healthful diet?. Prim Care, 1982, 9: 445-73. PMID:6924383. | Dependent variable
129 | Heim, T. Energy and lipid requirements of the fetus and the preterm infant. J Pediatr Gastroenterol Nutr, 1983, . PMID:6417303. | Independent variable, study design
130 | Hellmuth, C., Lindsay, K. L., Uhl, O. et al. Association of maternal prepregnancy BMI with metabolomic profile across gestation. Int J Obes (Lond), 2017, 41: 159-169. PMID:27569686. | Dependent variable
131 | Hennessy, M. D., Volpe, S. L., Sammel, M. D. et al. Skipping meals and less walking among African Americans diagnosed with preterm labor. J Nurs Scholarsh, 2010, 42: 147-55. PMID:20618599. | Independent variable
132 | Heppe, D. H., Steegers, E. A., Timmermans, S. et al. Maternal fish consumption, fetal growth and the risks of neonatal complications: the Generation R Study. Br J Nutr, 2011, 105: 938-49. PMID:21266095. | Independent variable
133 | Hernandez-Diaz, S., Boeke, C. E., Romans, A. T. et al. Triggers of spontaneous preterm delivery--why today?. Paediatr Perinat Epidemiol, 2014, 28: 79-87. PMID:24384058. | Independent variable, study design
134 | Herrera, Mg, Mora, Jo, Paredes, B et al. Maternal weight/height and the effect of food supplementation during pregnancy and lactation. Maternal Nutrition during Pregnancy and Lactation. A Nestle Foundation Workshop; 1979 April 26-27; Lausanne Switzerland, 1980, : 252-63 | Independent variable, not peer reviewed
135 | Hoff, C., Wertelecki, W., Reyes, E. et al. Diet, blood pressure, and hematologic variables of nulliparous women attending a prenatal clinic. Obstet Gynecol, 1986, 67: 868-72. PMID:3703412. | Independent variable
136 | Hoffman, D, Uauy, R, Birch, D et al. Essentiality of dietary docosahexaenoic acid (dha) for optimal visual maturation in preterm infants: plasma and red blood cell (rbc) fatty acid profiles. Iovs, 1992, 33 | Dependent variable
137 | Hoffman, Dr, Uauy, R. Essentiality of dietary n-3 fatty acids for premature infants; plasma and red blood cell fatty acid composition. Lipids, 1992, 27: 886-95 | Independent variable
138 | Hollingsworth, D. R., Ney, D., Stubblefield, N. et al. Metabolic and therapeutic assessment of gestational diabetes by two-hour and twenty-four-hour isocaloric meal tolerance tests. Diabetes, 1985, : 81-7. PMID:3888746. | Dependent variable
139 | Hook, E. B. Influence of pregnancy on dietary selection. Int J Obes, 1980, 4: 338-40. PMID:7419353. | Study design
140 | Horan, M. K., McGowan, C. A., Gibney, E. R. et al. Maternal low glycaemic index diet, fat intake and postprandial glucose influences neonatal adiposity--secondary analysis from the ROLO study. Nutr J, 2014, 13. PMID:25084967. | Independent variable
141 | Horan, M. K., McGowan, C. A., Gibney, E. R. et al. Maternal Nutrition and Glycaemic Index during Pregnancy Impacts on Offspring Adiposity at 6 Months of Age--Analysis from the ROLO Randomised Controlled Trial. Nutrients, 2016, 8. PMID:26742066. | Independent variable, dependent variable
142 | Horan, M. K., McGowan, C. A., Gibney, E. R. et al. Maternal nutrition and glycaemic index during pregnancy impacts on offspring adiposity at 6 months of ageâ€”analysis from the ROLO randomised controlled trial. Nutrients, 2016, 8. | Duplicate
143 | Huh, S. Y., Rifas-Shiman, S. L., Kleinman, K. P. et al. Maternal protein intake is not associated with infant blood pressure. Int J Epidemiol, 2005, 34: 378-84. PMID:15576466. | Independent variable
144 | Hui, A. L., Ludwig, S. M., Gardiner, P. et al. Community-based exercise and dietary intervention during pregnancy: A pilot study. Canadian Journal of Diabetes, 2006, 30: 169-175 | Independent variable
145 | Hui, A., Back, L., Ludwig, S. et al. Lifestyle intervention on diet and exercise reduced excessive gestational weight gain in pregnant women under a randomized controlled trial. Obstetrical and Gynecological Survey, 2012, 67: 263-264 | Independent variable
146 | Iyengar, L. Effects of dietary supplements late in pregnancy on the expectant mother and her newborn. Indian Journal of Medical Research, 1967, 55: 85-9 | Date
147 | Jedrychowski, W., Perera, F., Mrozek-Budzyn, D. et al. Higher fish consumption in pregnancy may confer protection against the harmful effect of prenatal exposure to fine particulate matter. Ann Nutr Metab, 2010, 56: 119-26. PMID:20134157. | Independent variable
148 | Jing, W., Huang, Y., Liu, X. et al. The effect of a personalized intervention on weight gain and physical activity among pregnant women in China. Int J Gynaecol Obstet, 2015, 129: 138-41. PMID:25697965. | Independent variable
149 | Johnson, A. A., Knight, E. M., Edwards, C. H. et al. Dietary intakes, anthropometric measurements and pregnancy outcomes. J Nutr, 1994, 124. PMID:8201444. | Independent variable
150 | Jovanovic-Peterson, L, Durak, Ep, Peterson, Cm. Randomized trial of diet vs diet plus cardiovascular conditioning on glucose levels in gestational diabetes. Am J Obstet Gynecol, 1989, 161: 415-9 | Health status
151 | Jovanovic-Peterson, L., Peterson, C. M. Turning point in the management of pregnancies complicated by diabetes. Normoglycemia with self blood glucose monitoring of diet and insulin dosing. ASAIO Trans, 1990, 36: 799-804. PMID:2268482. | Independent variable, study design
152 | Jowett, N. I., Nichol, S. G. Diabetic pregnancy. Midwives Chron, 1987, 100: 33-6. PMID:3645266. | Study design
153 | Kafatos, A. G., Vlachonikolis, I. G., Codrington, C. A. Nutrition during pregnancy: the effects of an educational intervention program in Greece. Am J Clin Nutr, 1989, 50: 970-9. PMID:2816804. | Independent variable
154 | Kalhan, S. C., Tserng, K. Y., Gilfillan, C. et al. Metabolism of urea and glucose in normal and diabetic pregnancy. Metabolism, 1982, 31: 824-33. PMID:7098852. | Dependent variable
155 | Kaseb, F., Kimiagar, M., Ghafarpoor, M. et al. Effect of traditional food supplementation during pregnancy on maternal weight gain and birthweight. Int J Vitam Nutr Res, 2002, 72: 389-93. PMID:12596505. | Independent variable
156 | Kelleher, C. C., Viljoen, K., Khalil, H. et al. Longitudinal follow-up of the relationship between dietary intake and growth and development in the Lifeways cross-generation cohort study 2001-2013. Proc Nutr Soc, 2014, 73: 118-31. PMID:24300176. | Study design
157 | Kesmodel, U., Olsen, S. F., Salvig, J. D. Marine n-3 fatty acid and calcium intake in relation to pregnancy induced hypertension, intrauterine growth retardation, and preterm delivery. A case-control study. Acta Obstet Gynecol Scand, 1997, 76: 38-44. PMID:9033242. | Independent variable
158 | Khoury, J, Haugen, G, Tonstad, S et al. Effect of an antiatherogenic diet on maternal and fetal Doppler velocimetry: a randomized clinical trial. 35th Nordic Congress of Obstetrics and Gynecology; 2006 May 23-25; Goteburg, Sweden, 2008, | Not peer-reviewed
159 | Khoury, J, Henriksen, T, Seljeflot, I et al. Effects of a cholesterol-lowering diet during pregnancy on cardiovascular risk factors and pregnany outcome: a randomized clinical trial [Study design]. Atherosclerosis. Supplements, 2006, 7 | Study design
160 | Khoury, J., Haugen, G., Tonstad, S. et al. Effect of a cholesterol-lowering diet during pregnancy on maternal and fetal Doppler velocimetry: the CARRDIP study. Am J Obstet Gynecol, 2007, 196. PMID:17547890. | Independent variable
161 | Kinnunen, T. I., Pasanen, M., Aittasalo, M. et al. Preventing excessive weight gain during pregnancy - a controlled trial in primary health care. Eur J Clin Nutr, 2007, 61: 884-91. PMID:17228348. | Independent variable
162 | Kinnunen, T. I., Puhkala, J., Raitanen, J. et al. Effects of dietary counselling on food habits and dietary intake of Finnish pregnant women at increased risk for gestational diabetes - a secondary analysis of a cluster-randomized controlled trial. Matern Child Nutr, 2014, 10: 184-97. PMID:22735030. | Independent variable, dependent variable
163 | Kizirian, N. V., Kong, Y., Muirhead, R. et al. Effects of a low-glycemic index diet during pregnancy on offspring growth, body composition, and vascular health: a pilot randomized controlled trial. Am J Clin Nutr, 2016, 103: 1073-82. PMID:26936333. | Independent variable
164 | Klebanoff, M. A., Harper, M., Lai, Y. et al. Fish consumption, erythrocyte fatty acids, and preterm birth. Obstet Gynecol, 2011, 117: 1071-7. PMID:21508745. | Independent variable
165 | Knudsen, V. K., Heitmann, B. L., Halldorsson, T. I. et al. Maternal dietary glycaemic load during pregnancy and gestational weight gain, birth weight and postpartum weight retention: a study within the Danish National Birth Cohort. Br J Nutr, 2013, 109: 1471-8. PMID:22906835. | Independent variable
166 | Knuist, M., Bonsel, G. J., Zondervan, H. A. et al. Low sodium diet and pregnancy-induced hypertension: a multi-centre randomised controlled trial. Br J Obstet Gynaecol, 1998, 105: 430-4. PMID:9609271. | Independent variable
167 | Koivusalo, S. B., Rono, K., Klemetti, M. M. et al. Gestational Diabetes Mellitus Can Be Prevented by Lifestyle Intervention: The Finnish Gestational Diabetes Prevention Study (RADIEL): A Randomized Controlled Trial. Diabetes Care, 2016, 39: 24-30. PMID:26223239. | Independent variable
168 | Kokanali, M. K., Tokmak, A., Kaymak, O. et al. The effect of treatment on pregnancy outcomes in women with one elevated oral glucose tolerance test value. Ginekol Pol, 2014, 85: 748-53. PMID:25546925. | Independent variable
169 | Kolu, P., Raitanen, J., Rissanen, P. et al. Cost-effectiveness of lifestyle counselling as primary prevention of gestational diabetes mellitus: findings from a cluster-randomised trial. PLoS One, 2013, 8. PMID:23457562. | Independent variable
170 | Korpi-Hyovalti, E., Schwab, U., Laaksonen, D. E. et al. Effect of intensive counselling on the quality of dietary fats in pregnant women at high risk of gestational diabetes mellitus. Br J Nutr, 2012, 108: 910-7. PMID:22093485. | Independent variable
171 | Kubota, K., Itoh, H., Tasaka, M. et al. Changes of maternal dietary intake, bodyweight and fetal growth throughout pregnancy in pregnant Japanese women. J Obstet Gynaecol Res, 2013, 39: 1383-90. PMID:23815608. | Independent variable
172 | Kumar, P., Nangia, S., Saili, A. et al. Growth and morbidity patterns of exclusively breast-fed preterm babies. Indian Pediatr, 1999, 36: 296-300. PMID:10713842. | Dependent variable
173 | Lakin, V., Haggarty, P., Abramovich, D. R. et al. Dietary intake and tissue concentration of fatty acids in omnivore, vegetarian and diabetic pregnancy. Prostaglandins Leukot Essent Fatty Acids, 1998, 59: 209-20. PMID:9844995. | Independent variable
174 | Langley-Evans, A. J., Langley-Evans, S. C. Relationship between maternal nutrient intakes in early and late pregnancy and infants weight and proportions at birth: prospective cohort study. J R Soc Promot Health, 2003, 123: 210-6. PMID:14669495. | Independent variable
175 | Laraia, B. A., Siega-Riz, A. M., Kaufman, J. S. et al. Proximity of supermarkets is positively associated with diet quality index for pregnancy. Prev Med, 2004, 39: 869-75. PMID:15475018. | Dependent variable
176 | Latva-Pukkila, U., Isolauri, E., Laitinen, K. Dietary and clinical impacts of nausea and vomiting during pregnancy. J Hum Nutr Diet, 2010, 23: 69-77. PMID:19943842. | Dependent variable
177 | Leblance, H., Passa, P. Diabetes and pregnancy. Revue du Praticien - Medecine Generale, 1992, 6: 577-582 | Study design, language
178 | Lechtig, A, Habicht, Jp, Delgado, H et al. Effect of food supplementation during pregnancy on birthweight. Pediatrics, 1975, 56: 508-20 | Date
179 | Lenders, C. M., Hediger, M. L., Scholl, T. O. et al. Gestational age and infant size at birth are associated with dietary sugar intake among pregnant adolescents. J Nutr, 1997, 127: 1113-7. PMID:9187625. | Independent variable
180 | Ley, S. H., Hanley, A. J., Retnakaran, R. et al. Effect of macronutrient intake during the second trimester on glucose metabolism later in pregnancy. Am J Clin Nutr, 2011, 94: 1232-40. PMID:21955650. | Independent variable, study design
181 | L’Heureux, J. Got sugar? Tips on preventing diabetes. Posit Living, 2002, 11: 12-4. PMID:12083048. | Study design
182 | Li, S., Zhu, Y., Chavarro, J. E. et al. Healthful Dietary Patterns and the Risk of Hypertension Among Women With a History of Gestational Diabetes Mellitus: A Prospective Cohort Study. Hypertension, 2016, 67: 1157-65. PMID:27091899. | Dependent variable
183 | Lilja, G, Dannaeus, A, Foucard, T et al. Effects of maternal diet during late pregnancy and lactation on the development of atopic disease in infants up to 18 months of age - in-vivo results. Clinical and Experimental Allergy, 1989, 19: 473-9 | Dependent variable
184 | Liu, X., Lv, L., Zhang, H. et al. Folic acid supplementation, dietary folate intake and risk of preterm birth in China. European Journal of Nutrition, 2016, 55: 1411-1422 | Independent variable, study design
185 | Lorber, D. Gestational diabetes: The hidden epidemic. Female Patient - Practical Ob/Gyn Medicine, 1990, 15: 15-25 | Study design
186 | Luoto, R, Nermes, M, Laitinen, K et al. Impact of Maternal Probiotic-Supplemented Dietary Counselling on Pregnancy Outcome and Prenatal and Postnatal Growth: A Double-Blind, Placebo-Controlled Study. Pediatric Academic Societies Annual Meeting; 2009 May 2 5; Baltimore MD, United States, 2009, | Not peer-reviewed
187 | MacGillivray, I. Aetiology of pre-eclampsia. Br J Hosp Med, 1981, 26. PMID:7296126. | Independent variable, study design
188 | MacNeill, S., Dodds, L., Hamilton, D. C. et al. Rates and risk factors for recurrence of gestational diabetes. Diabetes Care, 2001, 24: 659-62. PMID:11315827. | Independent variable
189 | Mahony, R, Byrne, J, Curran, S et al. A pilot study of the feasibility of a randomised trial of low glycaemic diet versus normal diet from early pregnancy in euglycaemic women. Arch Dis Child Fetal Neonatal Ed, 2008, 93 | Not peer-reviewed
190 | Makela, J., Lagstrom, H., Kaljonen, A. et al. Hyperglycemia and lower diet quality in pregnant overweight women and increased infant size at birth and at 13 months of age--STEPS study. Early Hum Dev, 2013, 89: 439-44. PMID:23375946. | Study design
191 | Maresh, M, Alderson, C, Beard, Rw et al. Comparison of insulin against diet treatment in the management of abnormal carbohydrate tolerance in pregnancy. Nutrition in Pregnancy. Proceedings of 10th Study Group of the Rcog; 1983, 1983, : 255-67 | Independent variable, not peer reviewed
192 | Mariscal-Arcas, M., Rivas, A., Monteagudo, C. et al. Proposal of a Mediterranean diet index for pregnant women. Br J Nutr, 2009, 102: 744-9. PMID:19243664. | Dependent variable
193 | Markovic, T. P., Muirhead, R., Overs, S. et al. Randomized Controlled Trial Investigating the Effects of a Low-Glycemic Index Diet on Pregnancy Outcomes in Women at High Risk of Gestational Diabetes Mellitus: The GI Baby 3 Study. Diabetes Care, 2016, 39: 31-8. PMID:26185283. | Independent variable
194 | Marshall, J. Infant feeding: 8. Breastfeeding premature babies. Pract Midwife, 2013, 16. PMID:23789255. | Dependent variable
195 | Martin, C. L., Siega-Riz, A. M., Sotres-Alvarez, D. et al. Maternal Dietary Patterns are Associated with Lower Levels of Cardiometabolic Markers during Pregnancy. Paediatr Perinat Epidemiol, 2016, 30: 246-55. PMID:26848932. | Study design
196 | Maten, Gd, Hammen, Rm, Visman, L et al. Effects of a sodium restricted diet during pregnancy on maternal blood pressure and zinc status. J Perinat Med, 1992, 20 | Independent variable
197 | Mathews, F., Yudkin, P., Neil, A. Influence of maternal nutrition on outcome of pregnancy: prospective cohort study. Bmj, 1999, 319: 339-43. PMID:10435950. | Independent variable
198 | Mathewson, M. Women diagnosed with pregnancy-induced hypertension (pre-eclampsia) should be placed on sodium restricted diets. Crit Care Nurse, 1983, 3. PMID:6552952. | Study design
199 | McFadyen, A. Intervention in mothers with eating disorders and their babies (controlled trial). National Research Register, 2000, | Not peer-reviewed
200 | McGowan, C. A., Walsh, J. M., Byrne, J. et al. The influence of a low glycemic index dietary intervention on maternal dietary intake, glycemic index and gestational weight gain during pregnancy: a randomized controlled trial. Nutr J, 2013, 12. PMID:24175958. | Independent variable
201 | McGuire, Mk, Burgert, Sl, Milner, Ja et al. Selenium status of infants is influenced by supplementation of formula or maternal diets. American Journal of Clinical Nutrition, 1993, 58: 643-8 | Independent variable
202 | Meinila, J., Koivusalo, S. B., Valkama, A. et al. Nutrient intake of pregnant women at high risk of gestational diabetes. Food Nutr Res, 2015, 59. PMID:25994096. | Dependent variable
203 | Meinila, J., Valkama, A., Koivusalo, S. B. et al. Healthy Food Intake Index (HFII) - Validity and reproducibility in a gestational-diabetes-risk population. BMC Public Health, 2016, 16. PMID:27475905. | Dependent variable
204 | Meltzer, H. M., Brantsaeter, A. L., Nilsen, R. M. et al. Effect of dietary factors in pregnancy on risk of pregnancy complications: results from the Norwegian Mother and Child Cohort Study. Am J Clin Nutr, 2011, 94. PMID:21543541. | Study design
205 | Mendelson, R., Dollard, D., Hall, P. et al. The impact of the Healthiest Babies Possible Program on maternal diet and pregnancy outcome in underweight and overweight clients. J Can Diet Assoc, 1991, 52: 229-34. PMID:10116012. | Independent variable
206 | Mendez, M. A., Plana, E., Guxens, M. et al. Seafood consumption in pregnancy and infant size at birth: results from a prospective Spanish cohort. J Epidemiol Community Health, 2010, 64: 216-22. PMID:19710045. | Independent variable
207 | Mestman, J. H. Outcome of diabetes screening in pregnancy and perinatal morbidity in infants of mothers with mild impairment in glucose tolerance. Diabetes Care, 1980, 3: 447-52. PMID:7389561. | Independent variable
208 | Mikkelsen, T. B., Osler, M., Orozova-Bekkevold, I. et al. Association between fruit and vegetable consumption and birth weight: a prospective study among 43,585 Danish women. Scand J Public Health, 2006, 34: 616-22. PMID:17132595. | Independent variable
209 | Mikode, M. S., White, A. A. Dietary assessment of middle-income pregnant women during the first, second, and third trimesters. J Am Diet Assoc, 1994, 94: 196-9. PMID:8300999. | Independent variable
210 | Misra, A., Ray, S., Patrikar, S. A longitudinal study to determine association of various maternal factors with neonatal birth weight at a tertiary care hospital. Med J Armed Forces India, 2015, 71: 270-3. PMID:26288495. | Country
211 | Mitchell, J., Mackerras, D. The traditional humoral food habits of pregnant Vietnamese-Australian women and their effect on birth weight. Aust J Public Health, 1995, 19: 629-33. PMID:8616205. | Independent variable
212 | Mohanty, A. F., Thompson, M. L., Burbacher, T. M. et al. Periconceptional Seafood Intake and Fetal Growth. Paediatr Perinat Epidemiol, 2015, 29: 376-87. PMID:26147526. | Independent variable
213 | Moldenhauer, J, Guo, S, Liang, R et al. Dietary intake levels of the antioxidants vitamin c and vitamin e are adequately achieved with standard prenatal vitamin supplementation in high risk pregnancy groups [abstract]. Am J Obstet Gynecol, 2002, 187 | Not peer-reviewed
214 | Moore, V. M., Davies, M. J., Willson, K. J. et al. Dietary composition of pregnant women is related to size of the baby at birth. J Nutr, 2004, 134: 1820-6. PMID:15226475. | Independent variable
215 | Morley, R, Lucas, A. Randomised diet in the neonatal period and growth performance until 7.5-8 y of age in preterm children. American Journal of Clinical Nutrition, 2000, 71: 822-8 | Dependent variable
216 | Morley, R., Lucas, A. Early diet and outcome in prematurely born. Clinical Nutrition, 1993, 12: 6-11 | Independent variable, health status
217 | Morrison, Ra, Brien, Pms, Micklewright, A. The effect of dietary supplementation with linoleic acid on the development of pregnancy induced hypertension. 4th World Congress of the International Society for the Study of Hypertension in Pregnancy;1984 June 18-21; Amsterdam, the Neth, 1984, | Not peer-reviewed
218 | Morrison, Ra, Brien, Pms. The effect of dietary supplementation with prostaglandin precursors in pregnancy induced hypertension (PIH). 5th International Congress of the International Society for the Study of Hypertension in Pregnancy; 1986 7-10 July, Nottingham,, 1986, | Not peer-reviewed
219 | Morton, N. E., Gulbrandsen, C. L., Rao, D. C. et al. Determinants of blood pressure in Japanese-American Families. Hum Genet, 1980, 53: 261-6. PMID:7358393. | Independent variable, health status
220 | Moses, R. G., Casey, S. A., Quinn, E. G. et al. Pregnancy and Glycemic Index Outcomes study: effects of low glycemic index compared with conventional dietary advice on selected pregnancy outcomes. Am J Clin Nutr, 2014, 99: 517-23. PMID:24351875. | Independent variable
221 | Moses, R. G., Luebcke, M., Davis, W. S. et al. Effect of a low-glycemic-index diet during pregnancy on obstetric outcomes. Am J Clin Nutr, 2006, 84: 807-12. PMID:17023707. | Independent variable
222 | Moses, R. G., Luebke, M., Petocz, P. et al. Maternal diet and infant size 2 y after the completion of a study of a low-glycemic-index diet in pregnancy [5]. American Journal of Clinical Nutrition, 2007, 86 | Duplicate
223 | Moses, Rg, Luebke, M, Petocz, P et al. Maternal diet and infant size 2 y after the completion of a study of a low-glycemic-index diet in pregnancy. American Journal of Clinical Nutrition, 2007, 86 | Dependent variable
224 | Moss, J. L., Harris, K. M. Impact of maternal and paternal preconception health on birth outcomes using prospective couples’ data in Add Health. Arch Gynecol Obstet, 2015, 291: 287-98. PMID:25367598. | Independent variable
225 | Mullaney, Laura, Brennan, Aisling, Cawley, Shona et al. Relationship between fasting plasma glucose levels and maternal food group and macronutrient intakes in pregnancy. Dietetics, 2016, 73: 441-447 | Independent variable
226 | Munson, M., Saatkamp, R., West, C. Late preterm infants: steps to success. Neonatal Netw, 2011, 30: 267-70. PMID:21729860. | Dependent variable
227 | Musaiger, A. O. Food habits of mothers and children in two regions of Oman. Nutr Health, 1996, 11: 29-48. PMID:8817582. | Independent variable, study design
228 | Musselman, J. R., Jurek, A. M., Johnson, K. J. et al. Maternal dietary patterns during early pregnancy and the odds of childhood germ cell tumors: A Children’s Oncology Group study. Am J Epidemiol, 2011, 173: 282-91. PMID:21098631. | Dependent variable
229 | Myhre, R., Brantsaeter, A. L., Myking, S. et al. Intakes of garlic and dried fruits are associated with lower risk of spontaneous preterm delivery. J Nutr, 2013, 143: 1100-8. PMID:23700347. | Independent variable
230 | Newman, Ak, Deussen, Ar, Moran, Lj et al. The effect of antenatal dietary and lifestyle advice on maternal psychological health in women who are overweight or obese-findings from the limit randomised trial. Journal of Paediatrics and Child Health [abstracts of the 17th Congress of the Perinatal Society of Australia and New Zealand, , 2013, 49 | Not peer-reviewed
231 | Ney, D., Hollingsworth, D. R., Cousins, L. Decreased insulin requirement and improved control of diabetes in pregnant women given a high-carbohydrate, high-fiber, low-fat diet. Diabetes Care, 1982, 5: 529-33. PMID:6329613. | Independent variable, health status
232 | Nicholls, M. G. Reduction of dietary sodium in Western Society. Benefit or risk?. Hypertension, 1984, 6: 795-801. PMID:6394485. | Study design
233 | Niedhammer, I., Murrin, C., O’Mahony, D. et al. Explanations for social inequalities in preterm delivery in the prospective Lifeways cohort in the Republic of Ireland. Eur J Public Health, 2012, 22: 533-8. PMID:21746747. | Independent variable
234 | Odent, M. Land food .. sea food .. brain food. Midwifery Today Childbirth Educ, 1996, : 18-20. PMID:9016057. | Study design
235 | Olafsdottir, A. S., Skuladottir, G. V., Thorsdottir, I. et al. Maternal diet in early and late pregnancy in relation to weight gain. Int J Obes (Lond), 2006, 30: 492-9. PMID:16331301. | Independent variable
236 | Olsen, S. F., Beck, D. N., Kollslid, R. et al. High birth weights in prewar Faroe Islands. J Epidemiol Community Health, 2001, 55. PMID:11160178. | Independent variable
237 | Olsen, S. F., Grandjean, P., Weihe, P. et al. Frequency of seafood intake in pregnancy as a determinant of birth weight: evidence for a dose dependent relationship. J Epidemiol Community Health, 1993, 47: 436-40. PMID:8120495. | Independent variable
238 | Olsen, S. F., Secher, N. J. Low consumption of seafood in early pregnancy as a risk factor for preterm delivery: prospective cohort study. Bmj, 2002, 324. PMID:11859044. | Independent variable
239 | Paisey, R. B., Hartog, M., Savage, P. A high-fibre diet in gestational diabetes--wheat fibre, leguminous fibre or both?. Hum Nutr Appl Nutr, 1987, 41: 146-9. PMID:3032872. | Study design
240 | Papadopoulou, E., Kogevinas, M., Botsivali, M. et al. Maternal diet, prenatal exposure to dioxin-like compounds and birth outcomes in a European prospective mother-child study (NewGeneris). Sci Total Environ, 2014, 484: 121-8. PMID:24691212. | Study design
241 | Papazian, T., Hout, H., Sibai, D. et al. Development, reproducibility and validity of a food frequency questionnaire among pregnant women adherent to the Mediterranean dietary pattern. Clinical Nutrition, 2016, 35: 1550-1556 | Dependent variable
242 | Pedersen, M., von Stedingk, H., Botsivali, M. et al. Birth weight, head circumference, and prenatal exposure to acrylamide from maternal diet: the European prospective mother-child study (NewGeneris). Environ Health Perspect, 2012, 120: 1739-45. PMID:23092936. | Study design
243 | Pentieva, K., Petrova, S., Ovcharova, D. et al. Influence of some sociodemographic factors and smoking on the risk for intrauterine growth retardation. Khigiena i Zdraveopazvane, 1996, 39: 5-8 | Language
244 | Perez-Ferre, N., Fernandez, D., Torrejon, M. J. et al. Effect of lifestyle on the risk of gestational diabetes and obstetric outcomes in immigrant Hispanic women living in Spain. J Diabetes, 2012, 4: 432-8. PMID:22742428. | Health status
245 | Persson, B, Stangenberg, M, Hansson, U et al. Gestational diabetes mellitus (GDM): comparative evaluation of two treatment regimens, diet vs insulin and diet. Diabetes, 1985, 34: 101-5 | Independent variable
246 | Petrella, E., Malavolti, M., Bertarini, V. et al. Gestational weight gain in overweight and obese women enrolled in a healthy lifestyle and eating habits program. J Matern Fetal Neonatal Med, 2014, 27: 1348-52. PMID:24175912. | Independent variable
247 | Petridou, E., Stoikidou, M., Diamantopoulou, M. et al. Diet during pregnancy in relation to birthweight in healthy singletons. Child Care Health Dev, 1998, 24: 229-42. PMID:9618037. | Independent variable, study design
248 | Phelan, S., Hart, C., Phipps, M. et al. Maternal behaviors during pregnancy impact offspring obesity risk. Exp Diabetes Res, 2011, 2011. PMID:22110475. | Independent variable
249 | Picaud, Jc, Lapillonne, A, Boucher, P et al. Dietary cholesterol does not affect vitamin D metabolism in preterm infants : preliminary results. Pediatr Res, 1999, 45 | Dependent variable
250 | Picone, T. A., Allen, L. H., Olsen, P. N. et al. Pregnancy outcome in North American women. II. Effects of diet, cigarette smoking, stress, and weight gain on placentas, and on neonatal physical and behavioral characteristics. Am J Clin Nutr, 1982, 36: 1214-24. PMID:7148740. | Independent variable
251 | Pinto, E., Barros, H., dos Santos Silva, I. Dietary intake and nutritional adequacy prior to conception and during pregnancy: a follow-up study in the north of Portugal. Public Health Nutr, 2009, 12: 922-31. PMID:18752697. | Independent variable, dependent variable
252 | Piraquive, J, Grieve, P, Sudha, K et al. Quality of Diet and Central Nervous System Activity in Low Birth Weight Infants. Pediatric Academic Societies Annual Meeting, 2013, | Independent variable
253 | Popeski, D., Ebbeling, L. R., Brown, P. B. et al. Blood pressure during pregnancy in Canadian Inuit: community differences related to diet. Cmaj, 1991, 145: 445-54. PMID:1878826. | Independent variable
254 | Qiu, C., Coughlin, K. B., Frederick, I. O. et al. Dietary fiber intake in early pregnancy and risk of subsequent preeclampsia. Am J Hypertens, 2008, 21: 903-9. PMID:18636070. | Independent variable
255 | Qiu, C., Zhang, C., Gelaye, B. et al. Gestational diabetes mellitus in relation to maternal dietary heme iron and nonheme iron intake. Diabetes Care, 2011, 34: 1564-9. PMID:21709295. | Independent variable
256 | Radder, J. K., Terpstra, J. Comparison of postprandial (lunch tolerance) and postglucose (oral glucose tolerance) blood sugar values in pregnancy. Eur J Obstet Gynecol Reprod Biol, 1980, 10: 163-71. PMID:7189481. | Independent variable
257 | Raman, L. Influence of maternal nutritional factors affecting birthweight. Am J Clin Nutr, 1981, 34: 775-83. PMID:7223693. | Country
258 | Ramon, R., Ballester, F., Aguinagalde, X. et al. Fish consumption during pregnancy, prenatal mercury exposure, and anthropometric measures at birth in a prospective mother-infant cohort study in Spain. Am J Clin Nutr, 2009, 90: 1047-55. PMID:19710189. | Independent variable
259 | Ramon, R., Ballester, F., Iniguez, C. et al. Vegetable but not fruit intake during pregnancy is associated with newborn anthropometric measures. J Nutr, 2009, 139: 561-7. PMID:19158218. | Independent variable
260 | Ramos-LevÃ, A. M., PÃ©rez-Ferre, N., FernÃ¡ndez, M. D. et al. Risk factors for gestational diabetes mellitus in a large population of women living in Spain: Implications for preventative strategies. International Journal of Endocrinology, 2012, 2012 | Independent variable, study design
261 | Ray, J. G., Mamdani, M. M. Association between folic acid food fortification and hypertension or preeclampsia in pregnancy. Arch Intern Med, 2002, 162: 1776-7. PMID:12153382. | Independent variable
262 | Reddy, S., Sanders, T. A., Obeid, O. The influence of maternal vegetarian diet on essential fatty acid status of the newborn. Eur J Clin Nutr, 1994, 48: 358-68. PMID:8055852. | Independent variable
263 | Reece, Ea, Gay, L, DeGennaro, N et al. A randomized clinical trial of a fiber-enriched diabetic diet vs the standard American Diabetes Association recommended diet in the management of diabetes mellitus in pregnancy. Proceedings of 10th Annual Meeting of Society of Perinatal Obstetricians; 1990 Jan 23-27; Houston, Texas, USA, 1990, | Not peer-reviewed
264 | Renzaho, A. M., Skouteris, H., Oldroyd, J. Preventing gestational diabetes mellitus among migrant women and reducing obesity and type 2 diabetes in their offspring: a call for culturally competent lifestyle interventions in pregnancy. J Am Diet Assoc, 2010, 110: 1814-7. PMID:21111090. | Study design
265 | Rhodes, E. T., Pawlak, D. B., Takoudes, T. C. et al. Effects of a low-glycemic load diet in overweight and obese pregnant women: a pilot randomized controlled trial. Am J Clin Nutr, 2010, 92: 1306-15. PMID:20962162. | Independent variable
266 | Ribeiro, M. D. Diet and pregnancy toxemia: new thoughts on an old problem. Public Health Rev, 1982, 10: 149-67. PMID:7167640. | Study design
267 | Rogers, I., Emmett, P., Baker, D. et al. Financial difficulties, smoking habits, composition of the diet and birthweight in a population of pregnant women in the South West of England. ALSPAC Study Team. Avon Longitudinal Study of Pregnancy and Childhood. Eur J Clin Nutr, 1998, 52: 251-60. PMID:9578337. | Independent variable
268 | Ross, Ra, Perlzweig, Wa, Taylor, Hm et al. A study of certain dietary factors of possible etiologic significance in toxemias of pregnancy. Am J Obstet Gynecol, 1938, 35: 426-40 | Date
269 | Ruiz-Gracia, T., Duran, A., Fuentes, M. et al. Lifestyle patterns in early pregnancy linked to gestational diabetes mellitus diagnoses when using IADPSG criteria. The St Carlos gestational study. Clin Nutr, 2016, 35: 699-705. PMID:25998584. | Independent variable
270 | Rush, D., Stein, Z., Susser, M. Diet in pregnancy: a randomized controlled trial of nutritional supplements. Birth Defects Orig Artic Ser, 1980, 16. PMID:7000197. | Independent variable
271 | Saldana, T. M., Siega-Riz, A. M., Adair, L. S. Effect of macronutrient intake on the development of glucose intolerance during pregnancy. Am J Clin Nutr, 2004, 79: 479-86. PMID:14985225. | Independent variable
272 | Sanders, T. A., Reddy, S. The influence of a vegetarian diet on the fatty acid composition of human milk and the essential fatty acid status of the infant. J Pediatr, 1992, 120. PMID:1560329. | Dependent variable
273 | Sauder, K. A., Starling, A. P., Shapiro, A. L. et al. Diet, physical activity and mental health status are associated with dysglycaemia in pregnancy: the Healthy Start Study. Diabet Med, 2016, 33: 663-7. PMID:26872289. | Study design
274 | Saunders, J. B. Investing in healthy babies. NCSL Legisbrief, 2009, 17: 1-2. PMID:19301480. | Not peer-reviewed
275 | Saunders, L., Guldner, L., Costet, N. et al. Effect of a Mediterranean diet during pregnancy on fetal growth and preterm delivery: results from a French Caribbean Mother-Child Cohort Study (TIMOUN). Paediatr Perinat Epidemiol, 2014, 28: 235-44. PMID:24754337. | Study design
276 | Savard, N., Levallois, P., Rivest, L. P. et al. Impact of individual and ecological characteristics on small for gestational age births: an observational study in Quebec. Chronic Dis Inj Can, 2014, 34: 46-54. PMID:24618381. | Independent variable
277 | Schneck, M. E., Sideras, K. S., Fox, R. A. et al. Low-income pregnant adolescents and their infants: dietary findings and health outcomes. J Am Diet Assoc, 1990, 90: 555-8. PMID:2319076. | Independent variable
278 | Scott, F. W., Kolb, H. Dietary intervention for diabetes prevention in the neonate. Diabetes Metab Rev, 1998, 14. PMID:9605633. | Study design
279 | Seely, E. W., Maxwell, C. Cardiology patient page. Chronic hypertension in pregnancy. Circulation, 2007, 115. PMID:17309919. | Independent variable, study design
280 | Sen, S., Rifas-Shiman, S. L., Shivappa, N. et al. Dietary Inflammatory Potential during Pregnancy Is Associated with Lower Fetal Growth and Breastfeeding Failure: Results from Project Viva. J Nutr, 2016, 146: 728-36. PMID:26936137. | Independent variable
281 | Shin, D., Lee, K. W., Song, W. O. Dietary Patterns during Pregnancy Are Associated with Risk of Gestational Diabetes Mellitus. Nutrients, 2015, 7: 9369-82. PMID:26569302. | Study design
282 | Siega-Riz, A. M., Herrmann, T. S., Savitz, D. A. et al. Frequency of eating during pregnancy and its effect on preterm delivery. Am J Epidemiol, 2001, 153: 647-52. PMID:11282791. | Independent variable
283 | Siega-Riz, A. M., Savitz, D. A., Zeisel, S. H. et al. Second trimester folate status and preterm birth. Am J Obstet Gynecol, 2004, 191: 1851-7. PMID:15592264. | Independent variable
284 | Simoes-Wust, A. P., Kummeling, I., Mommers, M. et al. Influence of alternative lifestyles on self-reported body weight and health characteristics in women. Eur J Public Health, 2014, 24: 321-7. PMID:23639916. | Independent variable
285 | Sister, MorningStar. Sick pregnancies. Midwifery Today Int Midwife, 2014, : 12-5. PMID:25980101. | Study design, non peer-reviewed
286 | Smeeth, L., Williams, D. Can a dietary supplement prevent pre-eclampsia? L-arginine with vitamins show promise, but there are good grounds for caution. Bmj, 2011, 342 | Independent variable
287 | Smith, L. K., Draper, E. S., Evans, T. A. et al. Associations between late and moderately preterm birth and smoking, alcohol, drug use and diet: a population-based case-cohort study. Arch Dis Child Fetal Neonatal Ed, 2015, 100. PMID:25972442. | Study design
288 | Smith, V. M. Preterm infant nutrition. Midwives Chron, 1989, 102: 143-6. PMID:2725350. | Study design
289 | Sokup, A., Mioduszewska, M., BaÌ§k, A. et al. Unhealthy eating habits precede gestational diabetes mellitus in Polish women Part I: Evaluation of frequency, regularity of consumed meals and consumed snacks, bread, sweets, fruit and vegetables. Eating habits and gestational diabetes. Diabetologia Doswiadczalna i Kliniczna, 2010, 10: 17-22 | Independent variable, health status
290 | Soto, R., Guilloty, N., Anzalota, L. et al. Association between maternal diet factors and hemoglobin levels, glucose tolerance, blood pressure and gestational age in a Hispanic population. Arch Latinoam Nutr, 2015, 65: 86-96. PMID:26817380. | Independent variable
291 | Souza, Lalitha, Jayaweera, Hiranthi, Pickett, Kate E. Pregnancy diets, migration, and birth outcomes. Health Care Women Int, 2016, 37: 964-978 | Study design
292 | Sparks, J. W. Fetal growth and diet. Mead Johnson Symp Perinat Dev Med, 1984, : 21-7. PMID:6545381. | Study design
293 | Standards of care of diabetes mellitus in pregnancy. Diabetologie Metabolismus Endokrinologie Vyziva, 2007, 10: 229-231 | Study design, language
294 | Steegers, E. A., Van Lakwijk, H. P., Jongsma, H. W. et al. (Patho)physiological implications of chronic dietary sodium restriction during pregnancy; a longitudinal prospective randomized study. Br J Obstet Gynaecol, 1991, 98: 980-7. PMID:1751444. | Independent variable
295 | Steegers, E. A. P., Van Lakwijk, H. P. J. M., Jongsma, H. W. et al. (Patho)physiological implications of chronic dietary sodium restriction during pregnancy; a longitudinal prospective randomzied study. Br J Obstet Gynaecol, 1991, 98: 980-987 | Duplicate
296 | Steegers, Eap, Buul, Eja. Chronic dietary sodium restriction in the prevention of hypertension during pregnancy: preliminary results of a Dutch multicentered trial. 9th International Congress of the International Society for the Study of Hypertension in Pregnancy; 1994 March 15-18; Sydney, A, 1994, | Not peer-reviewed
297 | Stein, A. Adressing disturbances in the relationship between mothers with eating disorders and their infants: a randomized controlled trial. Personal communication, 2004, | Independent variable, not peer reviewed
298 | Stein, A. The influence of maternal eating disorder on infant development: an intervention study. ControlledTrials.com [http://www.controlled-trials.com/ISRCTN95026274], 2004, | Independent variable, not peer reviewed
299 | Stephens, T. V., Woo, H., Innis, S. M. et al. Healthy pregnant women in Canada are consuming more dietary protein at 16- and 36-week gestation than currently recommended by the Dietary Reference Intakes, primarily from dairy food sources. Nutr Res, 2014, 34: 569-76. PMID:25150115. | Independent variable
300 | Stuckey-Schrock, K., Schrock, S. D. Head off complications in late preterm infants. J Fam Pract, 2013, 62. PMID:23570036. | Independent variable, study design
301 | Suhail, M., Suhail, M. F., Khan, H. Role of vitamins C and E in regulating antioxidant and pro-oxidant markers in preeclampsia. Journal of Clinical Biochemistry and Nutrition, 2008, 43: 210-220 | Country
302 | Svenningsen, Nw, Lindquist, B. Incidence of metabolic acidosis in term, preterm and small for gestational age infants in relation to dietary protein intake. Acta Paediatr Scand, 1973, 62: 1-10 | Date
303 | Switkowski, K. M., Jacques, P. F., Must, A. et al. Maternal protein intake during pregnancy and linear growth in the offspring. Am J Clin Nutr, 2016, 104: 1128-1136. PMID:27581477. | Independent variable
304 | Symonds, M. E., Budge, H., Edwards, L. J. et al. Maternal nutrition, cortisol and programming of fetal development. Perinatology, 2002, 4: 67-74 | No full text
305 | Tande, D. L., Ralph, J. L., Johnson, L. K. et al. First trimester dietary intake, biochemical measures, and subsequent gestational hypertension among nulliparous women. J Midwifery Womens Health, 2013, 58: 423-30. PMID:23895215. | Independent variable
306 | Tanha, F. D., Mohseni, M., Ghajarzadeh, M. et al. The effects of healthy diet in pregnancy. Journal of Family and Reproductive Health, 2013, 7: 121-125 | Independent variable, dependent variable
307 | Taylor, C. M., Golding, J., Emond, A. M. Blood mercury levels and fish consumption in pregnancy: Risks and benefits for birth outcomes in a prospective observational birth cohort. Int J Hyg Environ Health, 2016, 219: 513-20. PMID:27252152. | Independent variable
308 | Thacker, S. M., Petkewicz, K. A. Gestational diabetes mellitus. U.S. Pharm., 2009, 34: 43-48 | Study design
309 | Thomas, B., Ghebremeskel, K., Lowy, C. et al. Nutrient intake of women with and without gestational diabetes with a specific focus on fatty acids. Nutrition, 2006, 22: 230-6. PMID:16500549. | Independent variable, study design
310 | Thomas, D. M., Clapp, J. F., Shernce, S. A foetal energy balance equation based on maternal exercise and diet. J R Soc Interface, 2008, 5: 449-55. PMID:17895222. | Independent variable
311 | Thompson, J. M., Wall, C., Becroft, D. M. et al. Maternal dietary patterns in pregnancy and the association with small-for-gestational-age infants. Br J Nutr, 2010, 103: 1665-73. PMID:20211035. | Study design
312 | Tielemans, M. J., Erler, N. S., Leermakers, E. T. M. et al. A Priori and a Posteriori dietary patterns during pregnancy and gestational weight gain: The generation R study. Nutrients, 2015, 7: 9383-9399 | Dependent variable
313 | Tobias, D. K., Zhang, C., Chavarro, J. et al. Healthful dietary patterns and long-term weight change among women with a history of gestational diabetes mellitus. Int J Obes (Lond), 2016, 40: 1748-1753. PMID:27569683. | Dependent variable
314 | Tovar, A., Must, A., Bermudez, O. I. et al. The impact of gestational weight gain and diet on abnormal glucose tolerance during pregnancy in Hispanic women. Matern Child Health J, 2009, 13: 520-30. PMID:18597166. | Independent variable
315 | Uusitalo, U., Arkkola, T., Ovaskainen, M. L. et al. Unhealthy dietary patterns are associated with weight gain during pregnancy among Finnish women. Public Health Nutr, 2009, 12: 2392-9. PMID:19323867. | Dependent variable
316 | Valentini, R., Dalfra, M. G., Masin, M. et al. A pilot study on dietary approaches in multiethnicity: two methods compared. Int J Endocrinol, 2012, 2012. PMID:22505892. | Health status
317 | Van Buul, B. J. A., Steegers, E. A. P., Van Der Maten, G. D. et al. Dietary sodium restriction does not prevent gestational hypertension: A Dutch two-center randomized trial. Hypertension in Pregnancy, 1997, 16: 335-346 | Independent variable
318 | van Buul, B. J., Steegers, E. A., Jongsma, H. W. et al. Dietary sodium restriction in the prophylaxis of hypertensive disorders of pregnancy: effects on the intake of other nutrients. Am J Clin Nutr, 1995, 62: 49-57. PMID:7598066. | Independent variable
319 | van der Maten, G. D. Low sodium diet in pregnancy: effects on maternal nutritional status. Eur J Obstet Gynecol Reprod Biol, 1995, 61: 63-4. PMID:8549849. | Independent variable
320 | van der Maten, G. D., van Raaij, J. M., Visman, L. et al. Low-sodium diet in pregnancy: effects on blood pressure and maternal nutritional status. Br J Nutr, 1997, 77: 703-20. PMID:9175991. | Independent variable
321 | Vejrup, K., Brantsaeter, A. L., Knutsen, H. K. et al. Prenatal mercury exposure and infant birth weight in the Norwegian Mother and Child Cohort Study. Public Health Nutr, 2014, 17: 2071-80. PMID:24103413. | Independent variable
322 | Vilela, A. A., Pinto Tde, J., Rebelo, F. et al. Association of Prepregnancy Dietary Patterns and Anxiety Symptoms from Midpregnancy to Early Postpartum in a Prospective Cohort of Brazilian Women. J Acad Nutr Diet, 2015, 115: 1626-35. PMID:25769749. | Dependent variable
323 | Vitolo, Mr, Fraga, Bueno Ms, Mendes, Gama C. Impact of a dietary counseling program on the gain weight speed of pregnant women attended in a primary care service. Revista Brasileira de Ginecologia e Obstetricia, 2011, 33: 13-19 | Language
324 | Wakimoto, Patricia, Akabike, Andrea, King, Janet C. Maternal Nutrition and Pregnancy Outcomeâ€”A Look Back. Nutrition Today, 2015, 50: 221-229 | Study design, non peer-reviewed
325 | Walsh, J. M., Mahony, R. M., Culliton, M. et al. Impact of a low glycemic index diet in pregnancy on markers of maternal and fetal metabolism and inflammation. Reprod Sci, 2014, 21: 1378-81. PMID:24642719. | Dependent variable
326 | Walsh, J. M., McGowan, C. A., Mahony, R. et al. Low glycaemic index diet in pregnancy to prevent macrosomia (ROLO study): randomised control trial. Bmj, 2012, 345. PMID:22936795. | Independent variable
327 | Wang, C., Zhu, W., Wei, Y. et al. Exercise intervention during pregnancy can be used to manage weight gain and improve pregnancy outcomes in women with gestational diabetes mellitus. BMC Pregnancy Childbirth, 2015, 15. PMID:26459271. | Independent variable
328 | Weed, S. S. Preeclampsia. Midwifery Today Int Midwife, 2014, : 22-3. PMID:25980104. | Study design
329 | Wen, L. M., Simpson, J. M., Rissel, C. et al. Maternal junk food diet during pregnancy as a predictor of high birthweight: findings from the healthy beginnings trial. Birth, 2013, 40: 46-51. PMID:24635424. | Independent variable
330 | Wheeler, S. J., Poston, L., Thomas, J. E. et al. Maternal plasma fatty acid composition and pregnancy outcome in adolescents. Br J Nutr, 2011, 105: 601-10. PMID:21269546. | Independent variable
331 | Widga, A. C., Lewis, N. M. Defined, in-home, prenatal nutrition intervention for low-income women. J Am Diet Assoc, 1999, 99. PMID:10491673. | Independent variable
332 | Williams, C., Highley, W., Ma, E. H. et al. Protein, amino acid, and caloric intakes of selected pregnant women. J Am Diet Assoc, 1981, 78: 28-35. PMID:7217557. | Independent variable
333 | Williams, E. J. Gestational diabetes mellitus and diet control. Diabetes Educ, 1986, 12: 16-7. PMID:3633805. | Study design
334 | Wolff, C. B., Wolff, H. K. Maternal eating patterns and birth weight of Mexican American infants. Nutr Health, 1995, 10: 121-34. PMID:7491165. | Study design
335 | Wood,. Diet for diabetics: fact vs. hypothesis. Compr Ther, 1980, 6: 56-61. PMID:7408433. | Study design
336 | Wynn, A. H., Crawford, M. A., Doyle, W. et al. Nutrition of women in anticipation of pregnancy. Nutr Health, 1991, 7: 69-88. PMID:2038457. | Independent variable
337 | Zielinsky, P., Piccoli,, Vian, I. et al. Maternal restriction of polyphenols and fetal ductal dynamics in normal pregnancy: an open clinical trial. Arq Bras Cardiol, 2013, 101: 217-25. PMID:23949325. | Independent variable

3 Khoury, J., Henriksen, T., Seljeflot, I., Mørkrid, L., Frøslie, K. F., & Tonstad, S. (2007). Effects of an antiatherogenic diet during pregnancy on markers of maternal and fetal endothelial activation and inflammation: the CARRDIP study. BJOG, 114(3), 279–288. doi:10.1111/j.1471-0528.2006.01187.x 17217362

4 Dube, L., LeBel, J. L., & Lu, J. (2005). Affect asymmetry and comfort food consumption. Physiol Behav, 86(4), 559–567. doi:10.1016/j.physbeh.2005.08.023 16209880

5 Jeffery, R. W., Linde, J. A., Simon, G. E., Ludman, E. J., Rohde, P., Ichikawa, L. E., & Finch, E. A. (2009). Reported food choices in older women in relation to body mass index and depressive symptoms. Appetite, 52(1), 238–240. doi:10.1016/j.appet.2008.08.008 18801397

6 Agurs-Collins, T., & Fuemmeler, B. F. (2011). Dopamine polymorphisms and depressive symptoms predict foods intake. Results from a nationally representative sample. Appetite, 57(2), 339–348. doi:10.1016/j.appet.2011.05.325 21672565

10 Trichopoulou A, Costacou T, Bamia C, . (2003) Adherence to a Mediterranean diet and survival in a Greek population. N Engl J Med 348, 2599–2608.12826634

11 Collins CE, Young AF & Hodge A (2008) Diet quality is associated with higher nutrient intake and self-rated health in mid-aged women. J Am Coll Nutr 27, 146–157.18460493

12 Includes meal frequency, which is not included as a component in this table.

13 Mithril C, Dragsted LO, Meyer C . (2012) Guidelines for the New Nordic Diet. Public Health Nutr 15, 1941–1947.22251407

14 No reference provided.

15 Supplements and ‘other foods and beverages’ were also measured but not included in the score

16 Salmon and Trout excluded

17 Mariscal-Arcas, M., Rivas, A., Monteagudo, C., Granada, A., Cerrillo, I., Olea-Serrano, F., 2009. Proposal of a Mediterranean diet index for pregnant women. Br. J. Nutr. 102 (5), 744e749.19243664

18 S. L. Rifas-Shiman, J. W. Rich-Edwards, K. P. Kleinman, E. Oken, and M. W. Gillman, “Dietary quality during pregnancy varies by maternal characteristics in project viva: A US cohort,” Journal of the American Dietetic Association, vol. 109, no. 6, pp. 1004–1011, 2009.19465182

19 Trichopoulou A, Costacou T, Bamia C, . (2003) Adherence to a Mediterranean diet and survival in a Greek population. N Engl J Med 348, 2599–2608.12826634

20 McCullough ML, Feskanich D, Stampfer MJ, Giovannucci EL, Rimm EB, Hu FB, Spiegelman D, Hunter DJ, Colditz GA, Willett WC. Diet quality and major chronic disease risk in men and women: Moving toward improved dietary guidance. Am J Clin Nutr. 2002; 76:1261–1271.12450892

21 Guenther PM, Casavale KO, Reedy J, Kirkpatrick SI, Hiza HAB, Kuczynski KJ . Update of the Healthy Eating Index: HEI-2010. J Acad Nutr Diet 2013; 113:569–580.23415502

22 “Gender” was used here for consistency with the definition given in the article.

23 Lohman, T., Roche, A., Martorell, R., 1988. Anthropometric Standardization Reference Manual. Humana Kinetics Books, Illinois.

24 “Gender” was used here for consistency with the definition given in the article.

25 M. S. Kramer, R.W. Platt, S.W. Wen., “Anewand improved population-based Canadian reference for birth weight for gestational age,” Pediatrics, vol. 108, no. 2, article E35, 2001.11483845

26 Oken E, Kleinman KP, Rich-Edwards JW, Gillman MW. A nearly continuous measure of birth weight for gestational age using a United States national reference. BMC Pediatr. 2003; 3:6.12848901

27 Mamelle N, Boniol M, Rivie`re O, . Identification of newborns with fetal growth restriction (FGR) in weight and/or length based on constitutional growth potential. Eur J Pediatr 2006;165:717–25.16835759

28 Usher R, McLean F. Intrauterine growth of live-born Caucasian infants at sea level: standards obtained from measurements in 7 dimensions of infants born between 25 and 44 weeks of gestation. J Pediatr 1969;74:901–10.5781799

29 Mikolajczyk RT, Zhang J, Betran AP, Souza JP, Mori R, Gu¨lmezoglu AM, Merialdi M. A global reference for fetal-weight and birthweight percentiles. Lancet 2011;377:1855–61.21621717

30 Marsal K, Persson PH, Larsen T, Lilja H, Selbing A, Sultan B (1996). Intrauterine growth curves based on ultrasonically estimated foetal weights. Acta Paediatr 85, 843–848.8819552

31 He, J.R.; Xia, H.M.; Liu, Y.; Xia, X.Y.; Mo, W.J.; Wang, P.; Cheng, K.K.; Leung, G.M.; Feng, Q.; Schooling, C.M.; . A new birthweight reference in Guangzhou, southern china, and its comparison with the global reference. Arch. Dis. Child. 2014, 99, 1091–1097.24962952

32 Ministry of Health, Labor, and Welfare of Japan (2001) children and Infant Growth Survey on anthropometric parameters, 2000. http://www.mhlw.go.jp/houdou/0110/h1024-4.html (accessed December 2010).

33 Clapp JF (1996) Morphometric and neurodevelopmental outcome at age five years of the offspring of women who continued to exercise during pregnancy. J Pediatr 129:856–863 8969727

34 “Gender” was used here for consistency with the definition given in the article.

35 11 Skjærven R, Gjessing HK, Bakketeig LS. Birth weight by gestational age in Norway. Acta Obstet Gynecol Scand 2000;79:440–9.10857867

36 The authors measured IUGR but did not include it in outcome analyses.

37 Westerway, S. C., Papageorghiou, A. T., Hirst, J., Costa, F. D., Hyett, J., & Walker, S. P. (2015). INTERGROWTH-21st - Time to standardise fetal measurement in Australia. Australas J Ultrasound Med, 18(3), 91–95. doi:10.1002/j.2205-0140.2015.tb00206.x 28191248

38 U.S. Department of Health and Human Services and U.S. Department of Agriculture. (2015). 2015 – 2020 Dietary Guidelines for Americans. 8th Edition. Retrieved from https://health.gov/dietaryguidelines/2015/guidelines/.

39 Westerway, S. C., Papageorghiou, A. T., Hirst, J., Costa, F. D., Hyett, J., & Walker, S. P. (2015). INTERGROWTH-21st - Time to standardise fetal measurement in Australia. Australas J Ultrasound Med, 18(3), 91–95. doi:10.1002/j.2205-0140.2015.tb00206.x 28191248

40 Liese, A. D., Krebs-Smith, S. M., Subar, A. F., George, S. M., Harmon, B. E., Neuhouser, M. L., … Reedy, J. (2015). The Dietary Patterns Methods Project: synthesis of findings across cohorts and relevance to dietary guidance. J Nutr, 145(3), 393–402. doi:10.3945/jn.114.205336 25733454

41 For example, a study would be excluded from the systematic review if the dietary pattern were labeled “vegetarian” but lacked a description of what foods/beverages were consumed as part of that dietary pattern.