# List of abbreviations

Abbreviation: Full name
AHEI-2010: Alternative Healthy Eating Index – 2010
aMED: alternate Mediterranean diet score
BMD: Bone mineral density
BMI: Body mass index
CNPP: Center for Nutrition Policy and Promotion
CVD: Cardiovascular disease
DASH: Dietary Approaches to Stop Hypertension
EPIC: European Investigation into Cancer and Nutrition
EPITeen: Epidemiological Health Investigation of Teenagers in Portugal
FFQ: Food frequency questionnaire
FNS: Food and Nutrition Service
HHS: United States Department of Health and Human Services
KIDMED: Mediterranean Diet Quality Index for children and adolescents
mMDS: Modified Mediterranean diet score
mMED: Modified Mediterranean diet
NESR: Nutrition Evidence Systematic Review
OHS: Oslo Health Study
ONGA: Office of Nutrition Guidance and Analysis
PCS: Prospective cohort study
RCT: Randomized controlled trial
Ref: Reference
USDA: United States Department of Agriculture