# INTRODUCTION

This document describes a systematic review conducted to answer the following question: What is the relationship between dietary patterns consumed and bone health? This systematic review was conducted by the 2020 Dietary Guidelines Advisory Committee, supported by USDA’s Nutrition Evidence Systematic Review (NESR).

More information about the 2020 Dietary Guidelines Advisory Committee is available at the following website: www.DietaryGuidelines.gov.

NESR specializes in conducting food- and nutrition-related systematic reviews using a rigorous, protocol-driven methodology. More information about NESR is available at the following website: NESR.usda.gov.

NESR’s systematic review methodology involves developing a protocol, searching for and selecting studies, extracting data from and assessing the risk of bias of each included study, synthesizing the evidence, developing conclusion statements, grading the evidence underlying the conclusion statements, and recommending future research. A detailed description of the systematic reviews conducted for the 2020 Dietary Guidelines Advisory Committee, including information about methodology, used in conducting systematic reviews for the 2020 Dietary Guidelines Advisory Committee is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews. In addition, starting on page 27, this document describes the final protocol as it was applied in the systematic review. A description of and rationale for modifications made to the protocol are described in the 2020 Dietary Guidelines Advisory Committee Report, Part D: Chapter 8. Dietary Patterns.