# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this update to an existing systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this update to an existing systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^ix^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 8. Dietary Patterns.

The systematic review described in this document updates an existing systematic review conducted by the 2015 Dietary Guidelines Advisory Committee with support from USDA’s Nutrition Evidence Systematic Review (NESR) team. Information about the 2015 Dietary Guidelines Advisory Committee’s review of the evidence on dietary patterns and bone health can be found in their report, which is available at the following website: https://nesr.usda.gov/dietary-patterns-foods-and-nutrients-and-health-outcomes-subcommittee.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of this update to an existing systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, key confounders, and other factors to be considered. This is the analytic framework for the systematic review question on dietary patterns consumed and bone health. For this systematic review, the target population considered was children through older adults, who are healthy and/or at risk of chronic disease. The interventions or exposures considered were consumption of and/or adherence to a dietary pattern and their comparators were consumption of and/or adherence to a different dietary pattern or different levels of consumption of and/or adherence to a dietary pattern. The intermediate outcomes considered include bone mass, including bone mineral density and content, and biomarkers of bone metabolism. The endpoint outcomes are osteoporosis, osteopenia, rickets, and fracture. The key confounders are sex, age, race/ethnicity, socioecononic status, anthropometry, smoking, alcohol intake (in adults), physical activity, vitamin D status (e.g., sun exposure, use of vitamin D supplements, plasma or serum 25-OH-D levels), calcium supplements, and estrogen replacement therapy. Other factors to be considered include: total energy intake, medication use, family history of bone disease, malabsorptive conditions, lactose maldigestion, perceived milk intolerance, dairy allergy, postmenarcheal age (in children).

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for this update to an existing systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 3 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before and after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Case-control studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Studies that examine consumption of and/or adherence to a dietary pattern; - Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials; - Studies must describe the dietary pattern being tested or examined, including, at a minimum, the foods and beverages in the pattern | - Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern; - Studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed, as well as those patterns that are based solely on nutrients
Comparator | - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption of and/or adherence to a dietary pattern | N/A
Outcomes. ^x^ | Intermediate Outcomes:; - Bone mass including:; ○ Bone mineral density; ○ Bone mineral content; - Biomarkers of bone metabolism; Endpoint outcomes:; - Osteoporosis; - Osteopenia; - Rickets; - Fracture
Date of publication | January 2014 – November 2019 (this date range is in addition to the original systematic review, which included articles published from January 2000-January 2014) | Articles published prior to January 2014 or after November 2019
Publication status | Articles that have been peer-reviewed | Articles that have not been peer-reviewed and are not published in peer-reviewed journals (e.g., unpublished data, manuscripts, reports, abstracts, pre-prints, and conference proceedings)
Language of publication | Articles published in English | Articles published in languages other than English
Country. ^xi^ | Studies conducted in countries ranked as high or higher human development | Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants; - Males; - Females; - Women during pregnancy and lactation | Non-human participants (e.g., animal or in-vitro models)
Age of study participants | - Age at intervention or exposure:; ○ Children and adolescents (ages 2-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older); - Age at outcome:; ○ Children and adolescents (ages 2-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older) | - Age at intervention or exposure:; ○ Infants and toddlers (birth to 24 months); - Age at outcome; ○ Infants and toddlers (birth to 24 months)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease; ○ Studies that enroll some participants diagnosed with low bone mineral density, low bone mineral content, osteoporosis, osteopenia, rickets, and fracture | - Studies that exclusively enroll participants diagnosed with a disease or hospitalized with an illness or injury. (For this criterion, studies that exclusively enroll subjects with obesity will be included.); ○ Studies that exclusively enroll participants with osteoporosis, osteopenia, rickets, and fracture (i.e., studies that aim to treat participants who have already been diagnosed with the outcome of interest)
Study duration | - Minimum length of intervention of 12 weeks | - Interventions less than 12 weeks
Size of study groups | - 30 participants per arm in interventions, or a power calculation included; - Sample size of 1000 or greater in observational studies | - Fewer than 30 participants per arm, or; - No power calculation reported; - Fewer than 1000 participants in observational studies

### Electronic databases and search strategy

Listed below are the databases searched to identify all potentially relevant articles that have been published to address the update to an existing systematic review.

#### Search 1: Literature search to update the existing review from the 2015 Committee

##### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: November 15, 2019
- Date range searched: January 1, 2014 - November 15, 2019
- Search Terms:
  - #1 - dietary pattern* OR diet pattern* OR eating pattern* OR food pattern* OR diet quality* OR eating habit* OR dietary habit* OR diet habit* OR food habit* OR beverage habit* OR “Feeding Behavior”[Mesh:NoExp] OR dietary profile* OR food profile* OR diet profile* OR eating profile* OR dietary guideline* OR dietary recommendation* OR dietary intake* OR eating style* OR “Diet, Mediterranean”[Mesh] OR Mediterranean Diet*[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR Dietary Approaches To Stop Hypertension Diet* OR DASH diet* OR “Diet, Gluten-Free”[Mesh] OR Gluten Free diet* OR prudent diet* OR “Diet, Paleolithic”[Mesh] OR Paleolithic Diet* OR “Diet, Vegetarian”[Mesh] OR vegetarian diet*[tiab] OR vegan diet* OR “Diet, Healthy”[Mesh] OR plant based diet* OR “Diet, Western”[Mesh] OR western diet* OR “Diet, CarbohydrateRestricted”[Mesh] OR low-carbohydrate diet* OR high carbohydrate diet* OR Ketogenic Diet* OR Nordic Diet* OR “Diet, Fat-Restricted”[Mesh] OR “Diet, High-Fat”[Mesh] OR “Diet, High-Protein”[Mesh] OR high protein diet*[tiab] OR protein intake* OR high-fat diet* OR low fat diet* OR “Diet, Protein-Restricted”[Mesh] OR low protein diet* OR “Diet, Sodium-Restricted”[Mesh] OR low-sodium diet* OR low salt diet* OR ((“Dietary Proteins”[Mesh] OR dietary protein*[tiab] OR “Dietary Carbohydrates”[Mesh] OR dietary carbohydrate*[tiab] OR “Dietary Fats”[Mesh] OR dietary fat*[tiab] OR hypocaloric OR hypo-caloric) AND (diet[tiab] OR diets[tiab] OR consumption[tiab] OR intake[tiab] OR supplement*[tiab])) OR ((“Guideline Adherence”[Mesh] OR guideline adherence*)AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage*[tiab] OR nutrition*[tiab])) OR diet score* OR diet quality score* OR diet quality index* OR kidmed OR diet index* OR dietary index* OR food score* OR MedDietScore OR healthy eating index[tiab] OR ((pattern[tiab] OR patterns[tiab] OR consumption[tiab] OR habit*[tiab]) AND (“Diet”[Mesh:NoExp] OR diet[tiab] OR diets[tiab] OR dietary[tiab] OR “Food”[Mesh] OR food[tiab] OR foods[tiab] OR “Beverages”[Mesh] OR beverage[tiab] OR beverages[tiab]))
  - #2 - “Bone Density”[Mesh] OR “bone density”[tiab] OR bone mineral density[tiab] OR “Bone Development”[Mesh] OR “bone development”[tiab] OR “Fractures, Bone”[Mesh] OR bone fracture*[tiab] OR “Bone Diseases”[Mesh] OR bone disease*[tiab] OR bone turnover[tiab] OR bone loss[tiab] OR osteoporosis[tiab] OR “Osteoporosis”[Mesh] OR osteopen*[tiab] OR osteitis[tiab] OR “Rickets”[Mesh] OR Rickets[tiab] OR bone mineral*[tiab] OR “bone mass”[tiab] OR bone health*[tiab] OR “Bone Demineralization, Pathologic”[Mesh] OR bone demineral*[tiab] OR “Bone Remodeling”[Mesh] OR bone strength[tiab] OR bone formation[tiab] OR ((bone[tiab] OR bones[tiab] OR “Bone and Bones”[Mesh]) AND (fracture*[tiab] OR remodel*[tiab] OR formation*[tiab] OR osteolysis[tiab] OR ossification[tiab] OR resorption[tiab] OR accretion[tiab] OR BMC[tiab] OR BMD[tiab] OR “Biomarkers”[Mesh] OR biomarker*[tiab]))
  - #3 - (#1 AND #2)
  - #4 - (#1 AND #2) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2014/01/01 to 2019/11/15; English

##### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: November 15, 2019
- Date range searched: January 1, 2014 - November 15, 2019
- Search Terms:
  - #1 - (“dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality*” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR “beverage habit*” OR [mh ^“Feeding Behavior”] OR “dietary profile*” OR “food profile*” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR [mh “Diet, Mediterranean”] OR “Mediterranean Diet*” OR [mh “Dietary Approaches To Stop Hypertension”] OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR [mh “Diet, Gluten-Free”] OR “Gluten Free diet*” OR “prudent diet*” OR [mh “Diet, Paleolithic”] OR “Paleolithic Diet*” OR [mh “Diet, Vegetarian”] OR “vegetarian diet*” OR “vegan diet*” OR [mh “Diet, Healthy”] OR “plant based diet*” OR [mh “Diet, Western”] OR “western diet*” OR [mh “Diet, CarbohydrateRestricted”] OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, High-Protein”] OR “high protein diet*” OR “protein intake*” OR “high-fat diet*” OR “low fat diet*” OR [mh “Diet, Protein-Restricted”] OR “low protein diet*” OR [mh “Diet, Sodium-Restricted”] OR “low-sodium diet*” OR “low salt diet*”):ti,ab,kw
  - #2 - (([mh “Dietary Proteins”] OR “dietary protein*” OR [mh “Dietary Carbohydrates”] OR “dietary carbohydrate*” OR [mh “Dietary Fats”] OR “dietary fat*” OR hypocaloric OR hypo-caloric) NEAR/6 (diet OR diets OR consumption OR intake OR supplement*))
  - #3 – ([mh “Guideline Adherence”] OR guideline adherence*) NEAR/6 (diet OR dietary OR food OR beverage* OR nutrition*))
  - #4 - (“diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index*”):ti,ab,kw
  - #5 - (((pattern OR patterns OR consumption OR habit*) NEAR/6 ([mh ^Diet] OR diet OR diets OR dietary OR [mh Food] OR food OR foods OR [mh Beverages] OR beverage OR beverages))):ti,ab,kw
  - #6 - #1 OR #2 OR #3 OR #4 OR #5
  - #7 - [mh “Bone Density”] OR [mh “Bone Development”] OR [mh “Fractures, Bone”] OR [mh “Bone Diseases”] OR [mh Osteoporosis] OR [mh Rickets] OR [mh “Bone Demineralization, Pathologic”] OR [mh “Bone Remodeling”]
  - #8 - (“bone density” OR “bone mineral density” OR “bone development” OR “bone fracture*” OR “bone disease*” OR “bone turnover” OR “bone loss” OR osteoporosis OR osteopen* OR osteitis OR Rickets OR “bone mineral*” OR “bone mass” OR “bone health*” OR “bone demineral*” OR “bone strength” OR “bone formation”):ti,ab,kw
  - #9 - (((bone OR bones OR [mh “Bone and Bones”]) NEAR/6 (fracture* OR remodel* OR formation* OR osteolysis OR ossification OR resorption OR accretion OR BMC OR BMD OR [mh Biomarkers] OR biomarker*))):ti,ab,kw
  - #10 - #7 OR #8 OR #9
  - #11 - #6 AND #10” with Publication Year from 2014 to 2019, in Trials (Word variations have been searched)

##### Embase

- Provider: Elsevier
- Date(s) Searched: November 15, 2019
- Date range searched: January 1, 2014 – November 15, 2019
- Search Terms:
  - #1 - ‘feeding behavior’/de OR ‘mediterranean diet’/exp OR ‘dash diet’/exp OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/de OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein diet’/exp OR ‘protein restriction’/de OR ‘sodium restriction’/de
  - #2 - ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality*’:ab,ti OR ‘eating habit*’:ab,ti OR ‘dietary habit*’:ab,ti OR ‘diet habit*’:ab,ti OR ‘food habit*’:ab,ti OR ‘beverage habit*’:ab,ti OR ‘dietary profile*’:ab,ti OR ‘food profile*’:ab,ti OR ‘diet profile*’:ab,ti OR ‘eating profile*’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake*’:ab,ti OR ‘eating style*’:ab,ti OR ‘mediterranean diet*’:ab,ti OR ‘dietary approaches to stop hypertension diet*’:ab,ti OR ‘dash diet*’:ab,ti OR ‘gluten free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘paleolithic diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘low-carbohydrate diet*’:ab,ti OR ‘high carbohydrate diet*’:ab,ti OR ‘ketogenic diet*’:ab,ti OR ‘nordic diet*’:ab,ti OR ‘high protein diet*’:ab,ti OR ‘protein intake*’:ab,ti OR ‘high-fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low protein diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti
  - #3 - ((‘dietary protein*’ OR ‘dietary carbohydrate*’ OR ‘dietary fat*’ OR hypocaloric OR hypo-caloric) NEAR/6 (diet OR diets OR consumption OR intake OR supplement)):ab,ti
  - #4 - (‘guideline adherence’ NEAR/6 (diet OR dietary OR food OR beverage OR nutrition*)):ab,ti
  - #5 - ‘diet score’:ab,ti OR ‘diet quality score’:ab,ti OR kidmed:ab,ti OR ‘diet index’:ab,ti OR ‘dietary index’:ab,ti OR ‘diet quality index’:ab,ti OR ‘food score’:ab,ti OR meddietscore:ab,ti OR ‘healthy eating index’:ab,ti
  - #6 - ((pattern OR patterns OR consumption OR habit*) NEAR/6 (diet OR diets OR dietary OR food OR foods OR beverage OR beverages)):ab,ti
  - #7- #1 OR #2 OR #3 OR #4 OR #5 OR #6
  - #8 - ‘bone disease’/exp OR ‘bone density’/exp OR ‘bone development’/exp OR ‘fracture’/exp OR ‘osteoporosis’/exp OR ‘rickets’/exp OR ‘bone demineralization’/exp OR ‘bone remodeling’/exp
  - #9 - ‘bone density’:ab,ti OR ‘bone mineral density’:ab,ti OR ‘bone development’:ab,ti OR ‘bone fracture*’:ab,ti OR ‘bone disease*’:ab,ti OR ‘bone turnover’:ab,ti OR ‘bone loss’:ab,ti OR osteoporosis:ab,ti OR osteopen*:ab,ti OR osteitis:ab,ti OR rickets:ab,ti OR ‘bone mineral*’:ab,ti OR ‘bone mass’:ab,ti OR ‘bone health*’:ab,ti OR ‘bone demineral*’:ab,ti OR ‘bone strength’:ab,ti OR ‘bone formation’:ab,ti
  - #10 - ((bone OR bones) NEAR/6 (fracture* OR remodel* OR formation* OR osteolysis OR ossification OR resorption OR accretion OR bmc OR bmd OR biomarker*)):ab,ti
  - #11) #8 OR #9 OR #10
  - #12) #7 AND #11#13) #7 AND #11 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2014]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### Search 2: Additional search to cover diets based on macronutrient distribution

##### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: November 8, 2019
- Date range searched: January 1, 2000-December 31, 2014
- Search Terms:
  - #1 - Macronutrient* OR Macro-nutrient* OR “Dietary Carbohydrates”[Mesh] OR dietary carbohydrate* OR carbohydrate diet* OR “Diet, Carbohydrate-Restricted”[Mesh] OR carbohydrate-restrict* OR low carbohydrate* OR high carbohydrate* OR carbohydrate intake* OR “Dietary Proteins”[Mesh] OR protein diet* OR “Diet, Protein-Restricted”[Mesh] OR protein restrict* OR protein intake[tiab] OR low protein* OR “Diet, High-Protein”[Mesh] OR high protein* OR Ketogenic Diet* OR “Dietary Fats”[Mesh] OR dietary fat* OR fat intake* OR “Diet, High-Fat”[Mesh] OR high fat* OR “Diet, Fat-Restricted”[Mesh] OR fat-restricted* OR low fat*
  - #2 - “Bone Density”[Mesh] OR “bone density”[tiab] OR bone mineral density[tiab] OR “Bone Development”[Mesh] OR “bone development”[tiab] OR “Fractures, Bone”[Mesh] OR bone fracture*[tiab] OR “Bone Diseases”[Mesh] OR bone disease*[tiab] OR bone turnover[tiab] OR bone loss[tiab] OR osteoporosis[tiab] OR “Osteoporosis”[Mesh] OR osteopen*[tiab] OR osteitis[tiab] OR “Rickets”[Mesh] OR Rickets[tiab] OR bone mineral*[tiab] OR “bone mass”[tiab] OR bone health*[tiab] OR “Bone Demineralization, Pathologic”[Mesh] OR bone demineral*[tiab] OR “Bone Remodeling”[Mesh] OR bone strength[tiab] OR bone formation[tiab] OR ((bone[tiab] OR bones[tiab] OR “Bone and Bones”[Mesh]) AND (fracture*[tiab] OR remodel*[tiab] OR formation*[tiab] OR osteolysis[tiab] OR ossification[tiab] OR resorption[tiab] OR accretion[tiab] OR BMC[tiab] OR BMD[tiab] OR “Biomarkers”[Mesh] OR biomarker*[tiab]))
  - #3 - (#1 AND #2)
  - #4 - (#1 AND #2) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2000/01/01 to 2014/12/31; English

##### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: November 8, 2019
- Date range searched: January 1, 2000-December 31, 2014
- Search Terms:
  - #1 - [mh “Dietary Carbohydrates”] OR [mh “Diet, Carbohydrate-Restricted”] OR [mh “Dietary Proteins”] OR [mh “Diet, Protein-Restricted”] OR [mh “Diet, High-Protein”] OR [mh “Dietary Fats”] OR [mh “Diet, High-Fat”] OR [mh “Diet, Fat-Restricted”]
  - #2 - (macronutrient* OR macro-nutrient* OR “dietary carbohydrate*” OR “carbohydrate diet*” OR “carbohydrate-restrict*” OR “low carbohydrate*” OR “high carbohydrate*” OR “carbohydrate intake*” OR “protein diet*” OR “protein restrict*” OR “protein intake” OR “low protein*” OR “high protein*” OR “Ketogenic Diet*” OR “dietary fat*” OR “fat intake*” OR “high fat*” OR “fat-restricted*” OR “low fat*”):ti,ab,kw
  - #3 - #1 OR #2
  - #4 - [mh “Bone Density”] OR [mh “Bone Development”] OR [mh “Fractures, Bone”] OR [mh “Bone Diseases”] OR [mh Osteoporosis] OR [mh Rickets] OR [mh “Bone Demineralization, Pathologic”] OR [mh “Bone Remodeling”]
  - #5 - (“bone density” OR “bone mineral density” OR “bone development” OR “bone fracture*” OR “bone disease*” OR “bone turnover” OR “bone loss” OR osteoporosis OR osteopen* OR osteitis OR Rickets OR “bone mineral*” OR “bone mass” OR “bone health*” OR “bone demineral*” OR “bone strength” OR “bone formation”):ti,ab,kw
  - #6 - (((bone OR bones OR [mh “Bone and Bones”]) NEAR/6 (fracture* OR remodel* OR formation* OR osteolysis OR ossification OR resorption OR accretion OR BMC OR BMD OR [mh Biomarkers] OR biomarker*))):ti,ab,kw
  - #7 - #4 OR #5 OR #6
  - #8 - #3 AND #7” with Publication Year from 2000 to 2014, in Trials (Word variations have been searched)

##### Embase

- Provider: Elsevier
- Date(s) Searched: November 8, 2019
- Date range searched: January 1, 2000-December 31, 2014
- Search Terms:
  - #1- ‘macronutrient’/exp OR ‘carbohydrate diet’/exp OR ‘low carbohydrate diet’/exp OR ‘protein intake’/exp OR ‘protein restriction’/exp OR ‘protein diet’/exp OR ‘fat intake’/exp OR ‘lipid diet’/exp OR ‘low fat diet’/exp
  - #2 - macronutrient*:ab,ti OR ‘macro nutrient*’:ab,ti OR ‘dietary carbohydrate*’:ab,ti OR ‘carbohydrate diet*’:ab,ti OR ‘carbohydrate-restrict*’:ab,ti OR ‘low carbohydrate*’:ab,ti OR ‘high carbohydrate*’:ab,ti OR ‘carbohydrate intake*’:ab,ti OR ‘protein diet*’:ab,ti OR ‘protein restrict*’:ab,ti OR ‘protein intake’:ab,ti OR ‘low protein*’:ab,ti OR ‘high protein*’:ab,ti OR ‘ketogenic diet*’:ab,ti OR ‘dietary fat*’:ab,ti OR ‘fat intake*’:ab,ti OR ‘high fat*’:ab,ti OR ‘fat-restricted*’:ab,ti OR ‘low fat*’:ab,ti
  - #3 - #1 OR #2
  - #4 - ‘bone disease’/exp OR ‘bone density’/exp OR ‘bone development’/exp OR ‘fracture’/exp OR ‘osteoporosis’/exp OR ‘rickets’/exp OR ‘bone demineralization’/exp OR ‘bone remodeling’/exp
  - #5 - ‘bone density’:ab,ti OR ‘bone mineral density’:ab,ti OR ‘bone development’:ab,ti OR ‘bone fracture*’:ab,ti OR ‘bone disease*’:ab,ti OR ‘bone turnover’:ab,ti OR ‘bone loss’:ab,ti OR osteoporosis:ab,ti OR osteopen*:ab,ti OR osteitis:ab,ti OR rickets:ab,ti OR ‘bone mineral*’:ab,ti OR ‘bone mass’:ab,ti OR ‘bone health*’:ab,ti OR ‘bone demineral*’:ab,ti OR ‘bone strength’:ab,ti OR ‘bone formation’:ab,ti
  - #6 - ((bone OR bones) NEAR/6 (fracture* OR remodel* OR formation* OR osteolysis OR ossification OR resorption OR accretion OR bmc OR bmd OR biomarker*)):ab,ti
  - #7 - #4 OR #5 OR #6
  - #8 - #3 AND #7
  - #9 - #3 AND #7 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2014]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles in this update to an existing systematic review. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 4 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between dietary pattern consumption and bone health. The literature search yielded 3248 articles. During title screening, 2738 articles were screened out. During abstract screening, 345 articles were screened out. During full-text screening, 156 articles were screened out. During the hand search, 0 additional articles were identified to include. A total of 9 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles from updated literature search

The table below lists the articles excluded after full-text screening for the update to this systematic review question. At least one reason for exclusion is provided for each article, which may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table 4 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1 | Actrn,. 2008 Weight Loss, Protein and Bone Density study. http://www.who.int/trialsearch/Trial2.aspx?TrialID=ACTRN12608000229370. 2008. | Intervention/Exposure; Publication Status
2 | Alexy, U, Remer, T, Manz, F, Neu, CM, Schoenau, E. Long-term protein intake and dietary potential renal acid load are associated with bone modeling and remodeling at the proximal radius in healthy children. Am J Clin Nutr. 2005. 82:1107–14. doi:10.1093/ajcn/82.5.1107 16280446 | Intervention/Exposure
3 | Ambroszkiewicz, J, Chelchowska, M, Szamotulska, K, Rowicka, G, Klemarczyk, W, Strucinska, M, Gajewska, J. Bone status and adipokine levels in children on vegetarian and omnivorous diets. Clin Nutr. 2019. 38:730–737. doi:10.1016/j.clnu.2018.03.010 29609869 | Study Design
4 | Ambroszkiewicz, J, Chelchowska, M, Szamotulska, K, Rowicka, G, Klemarczyk, W, Strucinska, M, Gajewska, J. The Assessment of Bone Regulatory Pathways, Bone Turnover, and Bone Mineral Density in Vegetarian and Omnivorous Children. Nutrients. 2018. 10. doi:10.3390/nu10020183 | Study Design
5 | Antonio, J, Ellerbroek, A, Evans, C, Silver, T, Peacock, CA. High protein consumption in trained women: bad to the bone? J Int Soc Sports Nutr. 2018. 15:6. doi:10.1186/s12970-018-0210-6 29434529 | Intervention/Exposure
6 | Aparicio, VA, Ruiz-Cabello, P, Borges-Cosic, M, Andrade, A, Coll-Risco, I, Acosta-Manzano, P, Soriano-Maldonado, A. Association of physical fitness, body composition, cardiometabolic markers and adherence to the Mediterranean diet with bone mineral density in perimenopausal women. The FLAMENCO project. J Sports Sci. 2017. 35:880–887. doi:10.1080/02640414.2016.1196825 27310097 | Study Design
7 | Beasley, JM, Ichikawa, LE, Ange, BA, Spangler, L, LaCroix, AZ, Ott, SM, Scholes, D. Is protein intake associated with bone mineral density in young women? Am J Clin Nutr. 2010. 91:1311–6. doi:10.3945/ajcn.2009.28728 20219968 | Study Design; Intervention/Exposure
8 | Bielemann, RM, Dos, SVazJ, Domingues, MR, Matijasevich, A, Santos, IS, Ekelund, U, Horta, BL. Are consumption of dairy products and physical activity independently related to bone mineral density of 6-year-old children? Longitudinal and cross-sectional analyses in a birth cohort from Brazil. Public Health Nutr. 2018. 21:2654–2664. doi:10.1017/s1368980018001258 29766835 | Intervention/Exposure
9 | Bounds, W, Skinner, J, Carruth, BR, Ziegler, P. The relationship of dietary and lifestyle factors to bone mineral indexes in children. J Am Diet Assoc. 2005. 105:735–41. doi:10.1016/j.jada.2005.02.046 15883550 | Intervention/Exposure
10 | Bowen, J, Noakes, M, Clifton, P. High dairy-protein versus high mixed-protein energy restricted diets - the effect on bone turnover and calcium excretion in overweight adults. Asia pacific journal of clinical nutrition. 2003. 12 Suppl: S52. | Publication Date
11 | Bowen, J, Noakes, M, Clifton, PM. A high dairy protein, high-calcium diet minimizes bone turnover in overweight adults during weight loss. J Nutr. 2004. 134:568–73. doi:10.1093/jn/134.3.568 14988448 | Intervention/Exposure; Publication Date
12 | Brinkworth, G, Noakes, M, Buckley, J, Clifton, P. Long-term effects of a moderate energy restricted, very low carbohydrate diet on bone health in abdominally obese individuals. FASEB journal. 2011. 25. | Intervention/Exposure
13 | Brinkworth, GD, Wycherley, TP, Noakes, M, Buckley, JD, Clifton, PM. Long-term effects of a very-low-carbohydrate weight-loss diet and an isocaloric low-fat diet on bone health in obese adults. Nutrition. 2016. 32:1033–6. doi:10.1016/j.nut.2016.03.003 27157472 | Intervention/Exposure
14 | Brown, RC, Cox, CM, Goulding, A. High-carbohydrate versus high-fat diets: effect on body composition in trained cyclists. Med Sci Sports Exerc. 2000. 32:690–4. doi:10.1097/00005768-200003000-00021 10731014 | Intervention/Exposure
15 | Bullo, M, Amigo-Correig, P, Marquez-Sandoval, F, Babio, N, Martinez-Gonzalez, MA, Estruch, R, Basora, J, Sola, R, Salas-Salvado, J. Mediterranean diet and high dietary acid load associated with mixed nuts: effect on bone metabolism in elderly subjects. J Am Geriatr Soc. 2009. 57:1789–98. doi:10.1111/j.1532-5415.2009.02481.x 19807791 | Publication Date
16 | Campbell, WW, Tang, M. Protein intake, weight loss, and bone mineral density in postmenopausal women. J Gerontol A Biol Sci Med Sci. 2010. 65:1115–22. doi:10.1093/gerona/glq083 20605872 | Intervention/Exposure; Publication Date
17 | Cao, JJ, Johnson, LK, Hunt, JR. A diet high in meat protein and potential renal acid load increases fractional calcium absorption and urinary calcium excretion without affecting markers of bone resorption or formation in postmenopausal women. J Nutr. 2011. 141:391–7. doi:10.3945/jn.110.129361 21248199 | Publication Date
18 | Cao, JJ, Pasiakos, SM, Margolis, LM, Sauter, ER, Whigham, LD, McClung, JP, Young, AJ, Combs, GF, Jr. Calcium homeostasis and bone metabolic responses to high-protein diets during energy deficit in healthy young adults: a randomized controlled trial. Am J Clin Nutr. 2014. 99:400–7. doi:10.3945/ajcn.113.073809 24284444 | Intervention/Exposure
19 | Cao, JJ, Pasiakos, SM, Margolis, LM, Sauter, ER, Whigham, LD, McClung, JP, Young, AJ, Combs Jr, GF. Calcium homeostasis and bone metabolic responses to high-protein diets during energy deficit in healthy young adults: A randomized controlled trial1-4. American Journal of Clinical Nutrition. 2014. 99:400–407. doi:10.3945/ajcn.113.073809 | Intervention/Exposure
20 | Cao, JJ, Whigham, LD, Jahns, L. Depletion and repletion of fruit and vegetable intake alters serum bone turnover markers: a 28-week single-arm experimental feeding intervention. Br J Nutr. 2018. 120:500–507. doi:10.1017/s0007114518001642 30022739 | Study Design; Outcome
21 | Carter, JD, Vasey, FB, Valeriano, J. The effect of a low-carbohydrate diet on bone turnover. Osteoporos Int. 2006. 17:1398–403. doi:10.1007/s00198-006-0134-x 16718399 | Intervention/Exposure
22 | Casazza, K. A reduced carbohydrate diet results in loss in lean mass in peripubertal African American girls. FASEB journal. 2010. 24. | Intervention/Exposure; Outcome
23 | Cauley, JA, Cawthon, PM, Peters, KE, Cummings, SR, Ensrud, KE, Bauer, DC, Taylor, BC, Shikany, JM, Hoffman, AR, Lane, NE, Kado, DM, Stefanick, ML, Orwoll, ES. Risk Factors for Hip Fracture in Older Men: The Osteoporotic Fractures in Men Study (MrOS). J Bone Miner Res. 2016. 31:1810–1819. doi:10.1002/jbmr.2836 26988112 | Intervention/Exposure
24 | Chan, R, Woo, J, Lau, W, Leung, J, Xu, L, Zhao, X, Yu, W, Lau, E, Pocock, N. Effects of lifestyle and diet on bone health in young adult Chinese women living in Hong Kong and Beijing. Food Nutr Bull. 2009. 30:370–8. doi:10.1177/156482650903000408 20496627 | Intervention/Exposure
25 | Chen, Y, Xiang, J, Wang, Z, Xiao, Y, Zhang, D, Chen, X, Li, H, Liu, M, Zhang, Q. Associations of Bone Mineral Density with Lean Mass, Fat Mass, and Dietary Patterns in Postmenopausal Chinese Women: A 2-Year Prospective Study. PLoS One. 2015. 10:e0137097. doi:10.1371/journal.pone.0137097 26335921 | Outcome
26 | Chevalley, T, Bonjour, JP, Audet, MC, Merminod, F, van Rietbergen, B, Rizzoli, R, Ferrari, S. Prepubertal Impact of Protein Intake and Physical Activity on Weight-Bearing Peak Bone Mass and Strength in Males. J Clin Endocrinol Metab. 2017. 102:157–166. doi:10.1210/jc.2016-2449 27802093 | Intervention/Exposure
27 | Chevalley, T, Bonjour, JP, van Rietbergen, B, Ferrari, S, Rizzoli, R. Tracking of environmental determinants of bone structure and strength development in healthy boys: an eight-year follow up study on the positive interaction between physical activity and protein intake from prepuberty to mid-late adolescence. J Bone Miner Res. 2014. 29:2182–92. doi:10.1002/jbmr.2247 24715534 | Intervention/Exposure
28 | Clifton, PM, Noakes, M, Keogh, J, Foster, P. Effect of an energy reduced high protein red meat diet on weight loss and metabolic parameters in obese women. Asia pacific journal of clinical nutrition. 2003. 12 Suppl: S10. | Intervention/Exposure; Publication Date
29 | Colica, C, Merra, G, Gasbarrini, A, De Lorenzo, A, Cioccoloni, G, Gualtieri, P, Perrone, MA, Bernardini, S, Bernardo, V, Di Renzo, L, Marchetti, M. Efficacy and safety of very-low-calorie ketogenic diet: a double blind randomized crossover study. Eur Rev Med Pharmacol Sci. 2017. 21:2274–2289.28537652 | Intervention/Exposure
30 | Correa Rodriguez, M, Schmidt-RioValle, J, Rueda-Medina, B. Dietary antioxidant quality score (DAQs) is associated with bone mass assessed by calcaneal quantitative ultrasound in young women. Nutr Hosp. 2017. 34:613–618. doi:10.20960/nh.468 28627197 | Study Design
31 | Correa-Rodriguez, M, Schmidt-Rio Valle, J, de la Fuente-Vilchez, AM, Rueda-Medina, B. Analysis of lifestyle and bone mineralization in a population of Spanish young adults. Colomb Med (Cali). 2018. 49:213–218. doi:10.25100/cm.v49i2.2056 30410195 | Study Design
32 | Dai, Z, Butler, LM, van Dam, RM, Ang, LW, Yuan, JM, Koh, WP. Adherence to a vegetable-fruit-soy dietary pattern or the Alternative Healthy Eating Index is associated with lower hip fracture risk among Singapore Chinese. J Nutr. 2014. 144:511–8. doi:10.3945/jn.113.187955 24572035 | Country
33 | Dalskov, SM, Muller, M, Ritz, C, Damsgaard, CT, Papadaki, A, Saris, WH, Astrup, A, Michaelsen, KF, Molgaard, C. Effects of dietary protein and glycaemic index on biomarkers of bone turnover in children. Br J Nutr. 2014. 111:1253–62. doi:10.1017/s0007114513003760 24503413 | Intervention/Exposure
34 | Dawson-Hughes, B, Harris, SS. Calcium intake influences the association of protein intake with rates of bone loss in elderly men and women. Am J Clin Nutr. 2002. 75:773–9. doi:10.1093/ajcn/75.4.773 11916767 | Intervention/Exposure
35 | de Jonge, EA, Kiefte-de Jong, JC, de Groot, LC, Voortman, T, Schoufour, JD, Zillikens, MC, Hofman, A, Uitterlinden, AG, Franco, OH, Rivadeneira, F. Development of a Food Group-Based Diet Score and Its Association with Bone Mineral Density in the Elderly: The Rotterdam Study. Nutrients. 2015. 7:6974–90. doi:10.3390/nu7085317 26295256 | Outcome
36 | de Jonge, EAL, Rivadeneira, F, Erler, NS, Hofman, A, Uitterlinden, AG, Franco, OH, Kiefte-de Jong, JC. Dietary patterns in an elderly population and their relation with bone mineral density: the Rotterdam Study. Eur J Nutr. 2018. 57:61–73. doi:10.1007/s00394-016-1297-7 27557817 | Outcome
37 | Devine, A, Dick, IM, Islam, AF, Dhaliwal, SS, Prince, RL. Protein consumption is an important predictor of lower limb bone mass in elderly women. Am J Clin Nutr. 2005. 81:1423–8. doi:10.1093/ajcn/81.6.1423 15941897 | Intervention/Exposure
38 | Does protein benefit bone density? Health news (Waltham, Mass.). 2002. 8:9. | Publication Status
39 | Dorgan, JF, Liu, L, Klifa, C, Hylton, N, Shepherd, JA, Stanczyk, FZ, Snetselaar, LG, Van Horn, L, Stevens, VJ, Robson, A, Kwiterovich, PO, Jr, Lasser, NL, Himes, JH, Pettee Gabriel, K, Kriska, A, Ruder, EH, Fang, CY, Barton, BA. Adolescent diet and subsequent serum hormones, breast density, and bone mineral density in young women: results of the Dietary Intervention Study in Children follow-up study. Cancer Epidemiol Biomarkers Prev. 2010. 19:1545–56. doi:10.1158/1055-9965.Epi-09-1259 20501774 | Intervention/Exposure; Publication Date
40 | Draaisma, JMT, Hampsink, BM, Janssen, M, van Houdt, NBM, Linders, Etam, Willemsen, MA. The Ketogenic Diet and Its Effect on Bone Mineral Density: A Retrospective Observational Cohort Study. Neuropediatrics. 2019. doi:10.1055/s-0039-1693059 | Intervention/Exposure; Health Status
41 | Erkkila, AT, Sadeghi, H, Isanejad, M, Mursu, J, Tuppurainen, M, Kroger, H. Associations of Baltic Sea and Mediterranean dietary patterns with bone mineral density in elderly women. Public Health Nutr. 2017. 20:2735–2743. doi:10.1017/s1368980017001793 28803596 | Sample Size
42 | Fairweather-Tait, SJ, Skinner, J, Guile, GR, Cassidy, A, Spector, TD, MacGregor, AJ. Diet and bone mineral density study in postmenopausal women from the TwinsUK registry shows a negative association with a traditional English dietary pattern and a positive association with wine. Am J Clin Nutr. 2011. 94:1371–5. doi:10.3945/ajcn.111.019992 21940596 | Publication Date
43 | Fernandez-Real, JM, Bullo, M, Moreno-Navarrete, JM, Ricart, W, Ros, E, Estruch, R, Salas-Salvado, J. A Mediterranean diet enriched with olive oil is associated with higher serum total osteocalcin levels in elderly men at high cardiovascular risk. J Clin Endocrinol Metab. 2012. 97:3792–8. doi:10.1210/jc.2012-2221 22855341 | Publication Date
44 | Fitzmaurice, D, Doyle, L. The effect of a low-carbohydrate diet on biomarkers of bone health in pre-and post-menopausal females: a randomized control crossover trial. Proceedings of the nutrition society. 2011. 70:E355. doi:10.1017/S002966511100440X | Intervention/Exposure; Publication Status
45 | Forero-Bogota, MA, Ojeda-Pardo, ML, Garcia-Hermoso, A, Correa-Bautista, JE, Gonzalez-Jimenez, E, Schmidt-RioValle, J, Navarro-Perez, CF, Gracia-Marco, L, Vlachopoulos, D, Martinez-Torres, J, Ramirez-Velez, R. Body Composition, Nutritional Profile and Muscular Fitness Affect Bone Health in a Sample of Schoolchildren from Colombia: The Fuprecol Study. Nutrients. 2017. 9. doi:10.3390/nu9020106 | Study Design
46 | Foster, GD, Wyatt, HR, Hill, JO, Makris, AP, Rosenbaum, DL, Brill, C, Stein, RI, Mohammed, S, Miller, B, Rader, DJ, ,. Weight and metabolic outcomes after 2 years on a low-carbohydrate versus low-fat diet. Obstetrical & gynecological survey. 2010. 65:769–770. doi:10.1097/OGX.0b013e31821342ba | Intervention/Exposure; Publication Status
47 | Foster, GD, Wyatt, HR, Hill, JO, Makris, AP, Rosenbaum, DL, Brill, C, Stein, RI, Mohammed, BS, Miller, B, Rader, DJ, Zemel, B, Wadden, TA, Tenhave, T, Newcomb, CW, Klein, S. Weight and metabolic outcomes after 2 years on a low-carbohydrate versus low-fat diet: a randomized trial. Ann Intern Med. 2010. 153:147–57. doi:10.7326/0003-4819-153-3-201008030-00005 20679559 | Intervention/Exposure; Publication Date
48 | Frassetto, LA, Todd, KM, Morris, RC, Jr, Sebastian, A. Worldwide incidence of hip fracture in elderly women: relation to consumption of animal and vegetable foods. J Gerontol A Biol Sci Med Sci. 2000. 55:M585–92. doi:10.1093/gerona/55.10.m585 11034231 | Intervention/Exposure; Publication Date
49 | Fung, TT, Meyer, HE, Willett, WC, Feskanich, D. Protein intake and risk of hip fractures in postmenopausal women and men age 50 and older. Osteoporos Int. 2017. 28:1401–1411. doi:10.1007/s00198-016-3898-7 28074249 | Intervention/Exposure
50 | Gao, R, Duff, W, Chizen, D, Zello, GA, Chilibeck, PD. The effect of a low glycemic index pulse-based diet on insulin sensitivity, insulin resistance, bone resorption and cardiovascular risk factors during bed rest. Nutrients. 2019. 11. doi:10.3390/nu11092012 | Sample Size; Study Duration
51 | Go, G, Tserendejid, Z, Lim, Y, Jung, S, Min, Y, Park, H. The association of dietary quality and food group intake patterns with bone health status among Korean postmenopausal women: a study using the 2010 Korean National Health and Nutrition Examination Survey Data. Nutr Res Pract. 2014. 8:662–9. doi:10.4162/nrp.2014.8.6.662 25489406 | Study Design
52 | Greene, DA, Naughton, GA, Briody, JN, Kemp, A, Woodhead, H, Farpour-Lambert, N. Musculoskeletal health in elite male adolescent middle-distance runners. J Sci Med Sport. 2004. 7:373–83.15518302 | Intervention/Exposure
53 | Hannan, MT, Tucker, KL, Dawson-Hughes, B, Cupples, LA, Felson, DT, Kiel, DP. Effect of dietary protein on bone loss in elderly men and women: the Framingham Osteoporosis Study. J Bone Miner Res. 2000. 15:2504–12. doi:10.1359/jbmr.2000.15.12.2504 11127216 | Intervention/Exposure
54 | Hansen, TH, Madsen, MTB, Jorgensen, NR, Cohen, AS, Hansen, T, Vestergaard, H, Pedersen, O, Allin, KH. Bone turnover, calcium homeostasis, and vitamin D status in Danish vegans. Eur J Clin Nutr. 2018. 72:1046–1054. doi:10.1038/s41430-017-0081-y 29362456 | Study Design; Intervention/Exposure
55 | Harrington, M, Bennett, T, Jakobsen, J, Ovesen, L, Brot, C, Flynn, A, Cashman, KD. The effect of a high-protein, high-sodium diet on calcium and bone metabolism in postmenopausal women and its interaction with vitamin D receptor genotype. Br J Nutr. 2004. 91:41–51. doi:10.1079/bjn20031016 14748937 | Intervention/Exposure
56 | Harrington, M, Bennett, T, Jakobsen, J, Ovesen, L, Brot, C, Flynn, A, Cashman, KD. Effect of a high-protein, high-salt diet on calcium and bone metabolism in postmenopausal women stratified by hormone replacement therapy use. Eur J Clin Nutr. 2004. 58:1436–9. doi:10.1038/sj.ejcn.1601983 15100715 | Intervention/Exposure
57 | Hassoon, A, Appel, L, Miller, E. Effects of dietary patterns on vitamin D and other markers of bone-mineral metabolism: results from the DASH trial. Circulation. 2015. 131. | Publication Status
58 | Hassoon, A, Michos, ED, Miller, ER, Crisp, Z, Appel, LJ. Effects of Different Dietary Interventions on Calcitriol, Parathyroid Hormone, Calcium, and Phosphorus: Results from the DASH Trial. Nutrients. 2018. 10. doi:10.3390/nu10030367 | Sample Size; Study Duration
59 | Heer, M, Baecker, N, Frings-Meuthen, P, Graf, S, Zwart, SR, Biolo, G, Smith, SM. Effects of high-protein intake on bone turnover in long-term bed rest in women. Appl Physiol Nutr Metab. 2017. 42:537–546. doi:10.1139/apnm-2016-0292 28177714 | Intervention/Exposure
60 | High fat levels in muscles, liver, blood, and bone marrow linked to poor bone health.But a healthy weight and healthy diet can help stave off bone loss, osteoporosis. Duke Med Health News. 2013. 19:4–5. | Publication Date; Publication Status
61 | Ho-Pham, LT, Vu, BQ, Lai, TQ, Nguyen, ND, Nguyen, TV. Vegetarianism, bone loss, fracture and vitamin D: a longitudinal study in Asian vegans and non-vegans. Eur J Clin Nutr. 2012. 66:75–82. doi:10.1038/ejcn.2011.131 21811293 | Publication Date
62 | Hu, T, Rianon, NJ, Nettleton, JA, Hyder, JA, He, J, Steffen, LM, Jacobs, DR, Jr, Criqui, MH, Bazzano, LA. Protein intake and lumbar bone density: the Multi-Ethnic Study of Atherosclerosis (MESA). Br J Nutr. 2014. 112:1384–92. doi:10.1017/s0007114514002220 25192416 | Intervention/Exposure
63 | Hu, T, Yao, L, Bazzano, L. Effects of a 12-month low-carbohydrate diet vs. A low-fat diet on bone mineral density: a randomized controlled trial. FASEB journal. 2016. 30. | Intervention/Exposure
64 | Ince, BA, Anderson, EJ, Neer, RM. Lowering dietary protein to U.S. Recommended dietary allowance levels reduces urinary calcium excretion and bone resorption in young women. J Clin Endocrinol Metab. 2004. 89:3801–7. doi:10.1210/jc.2003-032016 15292308 | Intervention/Exposure
65 | Jajoo, R, Song, L, Rasmussen, H, Harris, SS, Dawson-Hughes, B. Dietary acid-base balance, bone resorption, and calcium excretion. J Am Coll Nutr. 2006. 25:224–30. doi:10.1080/07315724.2006.10719536 16766781 | Intervention/Exposure; Publication Date
66 | Jennings, A, Cashman, KD, Gillings, R, Cassidy, A, Tang, J, Fraser, W, Dowling, KG, Hull, GLJ, Berendsen, AAM, De Groot, LCPGM, Pietruszka, B, Wierzbicka, E, Ostan, R, Bazzocchi, A, Battista, G, Caumon, E, Meunier, N, Malpuech-Brugère, C, Franceschi, C, Santoro, A, Fairweather-Tait, SJ. A Mediterranean-like dietary pattern with Vitamin D3 (10 μg/d) supplements reduced the rate of bone loss in older Europeans with osteoporosis at baseline: Results of a 1-y randomized controlled trial. American Journal of Clinical Nutrition. 2018. 108:633–640. doi:10.1093/ajcn/nqy122 | Health Status
67 | Jennings, A, Cashman, KD, Gillings, R, Cassidy, A, Tang, J, Fraser, W, Dowling, KG, Hull, GLJ, Berendsen, AAM, de Groot, Lcpgm, ,. A Mediterranean-like dietary pattern with vitamin D3 (10 µg/d) supplements reduced the rate of bone loss in older Europeans with osteoporosis at baseline: results of a 1-y randomized controlled trial. American journal of clinical nutrition. 2018. 108:633–640. doi:10.1093/ajcn/nqy122 | Health Status
68 | Jesudason, D, Nordin, BC, Keogh, J, Clifton, P. Comparison of 2 weight-loss diets of different protein content on bone health: a randomized trial. Am J Clin Nutr. 2013. 98:1343–52. doi:10.3945/ajcn.113.058586 24047916 | Intervention/Exposure; Publication Date
69 | Josse, AR, Atkinson, SA, Tarnopolsky, MA, Phillips, SM. Diets higher in dairy foods and dietary protein support bone health during diet- and exercise-induced weight loss in overweight and obese premenopausal women. J Clin Endocrinol Metab. 2012. 97:251–60. doi:10.1210/jc.2011-2165 22049177 | Publication Date
70 | Kerstetter, JE, Looker, AC, Insogna, KL. Low dietary protein and low bone density. Calcif Tissue Int. 2000. 66:313. doi:10.1007/s002230010062 10742451 | Intervention/Exposure; Publication Status
71 | Kerstetter, JE, O’Brien, KO, Caseria, DM, Wall, DE, Insogna, KL. The impact of dietary protein on calcium absorption and kinetic measures of bone turnover in women. J Clin Endocrinol Metab. 2005. 90:26–31. doi:10.1210/jc.2004-0179 15546911 | Intervention/Exposure
72 | Kim, HS, Sohn, C, Kwon, M, Na, W, Shivappa, N, Hebert, JR, Kim, MK. Positive Association between Dietary Inflammatory Index and the Risk of Osteoporosis: Results from the KoGES_Health Examinee (HEXA) Cohort Study. Nutrients. 2018. 10. doi:10.3390/nu10121999 | Intervention/Exposure
73 | Kim, MH, Lee, JS, Johnson, MA. Poor Socioeconomic and Nutritional Status Are Associated with Osteoporosis in Korean Postmenopausal Women: Data from the Fourth Korea National Health and Nutrition Examination Survey (KNHANES) 2009. J Am Coll Nutr. 2015. 34:400–7. doi:10.1080/07315724.2014.945197 25826107 | Study Design
74 | Kontogianni, MD, Melistas, L, Yannakoulia, M, Malagaris, I, Panagiotakos, DB, Yiannakouris, N. Association between dietary patterns and indices of bone mass in a sample of Mediterranean women. Nutrition. 2009. 25:165–71. doi:10.1016/j.nut.2008.07.019 18849146 | Publication Date
75 | Langsetmo, L, Barr, SI, Berger, C, Kreiger, N, Rahme, E, Adachi, JD, Papaioannou, A, Kaiser, SM, Prior, JC, Hanley, DA, Kovacs, CS, Josse, RG, Goltzman, D. Associations of Protein Intake and Protein Source with Bone Mineral Density and Fracture Risk: A Population-Based Cohort Study. J Nutr Health Aging. 2015. 19:861–8. doi:10.1007/s12603-015-0544-6 26412291 | Intervention/Exposure
76 | Langsetmo, L, Barr, SI, Dasgupta, K, Berger, C, Kovacs, CS, Josse, RG, Adachi, JD, Hanley, DA, Prior, JC, Brown, JP, Morin, SN, Davison, KS, Goltzman, D, Kreiger, N. Dietary patterns in men and women are simultaneously determinants of altered glucose metabolism and bone metabolism. Nutr Res. 2016. 36:328–336. doi:10.1016/j.nutres.2015.12.010 27001278 | Outcome
77 | Langsetmo, L, Shikany, JM, Cawthon, PM, Cauley, JA, Taylor, BC, Vo, TN, Bauer, DC, Orwoll, ES, Schousboe, JT, Ensrud, KE. The Association Between Protein Intake by Source and Osteoporotic Fracture in Older Men: A Prospective Cohort Study. J Bone Miner Res. 2017. 32:592–600. doi:10.1002/jbmr.3058 27943394 | Intervention/Exposure
78 | Lee, H, Choi-Kwon, S, Choi, SH. The Effects of Korean DASH Diet Education with Calcium/Vitamin D Supplements on Nutrient Intakes, Food Consumption, Bone Turnover Markers and Bone Mineral Density among Korean Elderly Women. Korean j adult nurs. 2015. 27:94–105. doi:10.7475/kjan.2015.27.1.94 | Intervention/Exposure
79 | Leung, SS, Lee, RH, Sung, RY, Luo, HY, Kam, CW, Yuen, MP, Hjelm, M, Lee, SH. Growth and nutrition of Chinese vegetarian children in Hong Kong. J Paediatr Child Health. 2001. 37:247–53. doi:10.1046/j.1440-1754.2001.00647.x 11468039 | Publication Date
80 | Li, SKY, Wan, MMP, Siu, FPL, Chung, S, Pang, MYC. Relationship Between Nutritional Factors and Hip Bone Density in Individuals with Chronic Stroke. Calcif Tissue Int. 2017. 101:259–270. doi:10.1007/s00223-017-0276-1 28417148 | Intervention/Exposure
81 | Li, Z, Treyzon, L, Chen, S, Yan, E, Thames, G, Carpenter, CL. Protein-enriched meal replacements do not adversely affect liver, kidney or bone density: an outpatient randomized controlled trial. Nutr J. 2010. 9:72. doi:10.1186/1475-2891-9-72 21194471 | Intervention/Exposure; Publication Date
82 | Lousuebsakul-Matthews, V, Thorpe, DL, Knutsen, R, Beeson, WL, Fraser, GE, Knutsen, SF. Legumes and meat analogues consumption are associated with hip fracture risk independently of meat intake among Caucasian men and women: the Adventist Health Study-2. Public Health Nutr. 2014. 17:2333–43. doi:10.1017/s1368980013002693 24103482 | Intervention/Exposure
83 | Luscombe-Marsh, ND, Noakes, M, Wittert, GA, Keogh, JB, Foster, P, Clifton, PM. Carbohydrate-restricted diets high in either monounsaturated fat or protein are equally effective at promoting fat loss and improving blood lipids. Am J Clin Nutr. 2005. 81:762–72. doi:10.1093/ajcn/81.4.762 15817850 | Intervention/Exposure
84 | Mangano, KM, Sahni, S, Kiel, DP, Tucker, KL, Dufour, AB, Hannan, MT. Dietary protein is associated with musculoskeletal health independently of dietary pattern: the Framingham Third Generation Study. Am J Clin Nutr. 2017. 105:714–722. doi:10.3945/ajcn.116.136762 28179224 | Outcome
85 | Marcason, W. What is the effect of a high-protein diet on bone health? J Am Diet Assoc. 2010. 110:812. doi:10.1016/j.jada.2010.03.034 20430143 | Intervention/Exposure; Publication Date
86 | McCarter, DF. Low-carbohydrate diet effective for adults. Journal of family practice. 2003. 52:515–516. | Study Design; Intervention/Exposure; Publication Status
87 | McTiernan, A, Wactawski-Wende, J, Wu, L, Rodabough, RJ, Watts, NB, Tylavsky, F, Freeman, R, Hendrix, S, Jackson, R. Low-fat, increased fruit, vegetable, and grain dietary pattern, fractures, and bone mineral density: the Women’s Health Initiative Dietary Modification Trial. Am J Clin Nutr. 2009. 89:1864–76. doi:10.3945/ajcn.2008.26956 19403636 | Publication Date
88 | Melaku, YA, Gill, TK, Adams, R, Shi, Z. Association between dietary patterns and low bone mineral density among adults aged 50 years and above: findings from the North West Adelaide Health Study (NWAHS). Br J Nutr. 2016. 116:1437–1446. doi:10.1017/s0007114516003366 27669817 | Study Design
89 | Melaku, YA, Gill, TK, Appleton, SL, Taylor, AW, Adams, R, Shi, Z. Prospective Associations of Dietary and Nutrient Patterns with Fracture Risk: A 20-Year Follow-Up Study. Nutrients. 2017. 9. doi:10.3390/nu9111198 | Country
90 | Melaku, YA, Gill, TK, Taylor, AW, Adams, R, Shi, Z. A comparison of principal component analysis, partial least-squares and reduced-rank regressions in the identification of dietary patterns associated with bone mass in ageing Australians. Eur J Nutr. 2018. 57:1969–1983. doi:10.1007/s00394-017-1478-z 28608321 | Outcome
91 | Melaku, YA, Gill, TK, Taylor, AW, Adams, R, Shi, Z. Association between nutrient patterns and bone mineral density among ageing adults. Clin Nutr ESPEN. 2017. 22:97–106. doi:10.1016/j.clnesp.2017.08.001 29415843 | Intervention/Exposure; Outcome
92 | Meng, X, Zhu, K, Devine, A, Kerr, DA, Binns, CW, Prince, RL. A 5-year cohort study of the effects of high protein intake on lean mass and BMC in elderly postmenopausal women. J Bone Miner Res. 2009. 24:1827–34. doi:10.1359/jbmr.090513 19419320 | Intervention/Exposure
93 | Merrilees, MJ, Smart, EJ, Gilchrist, NL, Frampton, C, Turner, JG, Hooke, E, March, RL, Maguire, P. Effects of diary food supplements on bone mineral density in teenage girls. Eur J Nutr. 2000. 39:256–62. doi:10.1007/s003940070004 11395985 | Intervention/Exposure; Publication Date
94 | Misra, D, Berry, SD, Broe, KE, McLean, RR, Cupples, LA, Tucker, KL, Kiel, DP, Hannan, MT. Does dietary protein reduce hip fracture risk in elders? The Framingham Osteoporosis Study. Osteoporos Int. 2011. 22:345–9. doi:10.1007/s00198-010-1179-4 20442986 | Intervention/Exposure; Publication Date
95 | Moradi, S, Khorrami-Nezhad, L, Ali-Akbar, S, Zare, F, Alipour, T, Dehghani Kari Bozorg, A, Yekaninejad, MS, Maghbooli, Z, Mirzaei, K. The associations between dietary patterns and bone health, according to the TGF-beta1 T869-->C polymorphism, in postmenopausal Iranian women. Aging Clin Exp Res. 2018. 30:563–571. doi:10.1007/s40520-017-0828-2 28918533 | Study Design
96 | Moradi, S, Khorrami-nezhad, L, Ali-akbar, S, Zare, F, Alipour, T, Dehghani Kari Bozorg, A, Yekaninejad, MS, Maghbooli, Z, Mirzaei, K. The associations between dietary patterns and bone health, according to the TGF-β1 T869→C polymorphism, in postmenopausal Iranian women. Aging Clinical and Experimental Research. 2018. 30:563–571. doi:10.1007/s40520-017-0828-2 28918533 | Study Design
97 | Movassagh, EZ, Baxter-Jones, ADG, Kontulainen, S, Whiting, S, Szafron, M, Vatanparast, H. Vegetarian-style dietary pattern during adolescence has long-term positive impact on bone from adolescence to young adulthood: a longitudinal study. Nutr J. 2018. 17:36. doi:10.1186/s12937-018-0324-3 29490662 | Study Design; Outcome
98 | Munshi, R, Kochhar, A, Garg, V. Impact of Dietary Habits and Physical Activity on Bone Health among 40 to 60 Year Old Females at Risk of Osteoporosis in India. Ecol Food Nutr. 2015. 54:470–92. doi:10.1080/03670244.2015.1015120 25782139 | Intervention/Exposure
99 | Nakayama, A, Lutz, L, Hruby, A, Karl, JP, McClung, J, Gaffney-Stomberg, E. A dietary pattern rich in calcium, potassium, and protein is associated with tibia bone mineral content and strength in young adults entering initial military training. Journal of bone and mineral research. 2017. 32:S369. doi:10.1002/jbmr.3363 | Study Design
100 | Nct, Meat Protein and Calcium: do They Interact Synergistically or Antagonistically? https://clinicaltrials.gov/show/NCT00700804. 2008. | Publication Date; Publication Status
101 | Nct,. Effect of Diet Composition on Weight Change and Metabolic Parameters. https://clinicaltrials.gov/show/NCT01642849. 2012. | Study Design; Intervention/Exposure
102 | Nct,. Effectiveness of a Low Carbohydrate Diet Versus a High Carbohydrate Diet in Promoting Weight Loss and Improved Health. https://clinicaltrials.gov/show/NCT00200720. 2005. | Study Design; Publication Status
103 | Nieves, JW, Melsop, K, Curtis, M, Kelsey, JL, Bachrach, LK, Greendale, G, Sowers, MF, Sainani, KL. Nutritional factors that influence change in bone density and stress fracture risk among young female cross-country runners. Pm r. 2010. 2:740–50; quiz 794. doi:10.1016/j.pmrj.2010.04.020 20709302 | Publication Date
104 | Nowson, CA, Patchett, A, Wattanapenpaiboon, N. The effects of a low-sodium base-producing diet including red meat compared with a high-carbohydrate, low-fat diet on bone turnover markers in women aged 45-75 years. Br J Nutr. 2009. 102:1161–70. doi:10.1017/s0007114509371731 19445819 | Publication Date
105 | Nutrient-rich diet linked to reduction in fracture risk. Eating fruits, vegetables and whole grains is deemed key to bone health. Duke Med Health News. 2011. 17:7. | Publication Date; Publication Status
106 | Oh, SM, Kim, HC, Rhee, Y, Park, SJ, Lee, HJ, Suh, I, Feskanich, D. Dietary protein in relation to bone stiffness index and fat-free mass in a population consuming relatively low protein diets. J Bone Miner Metab. 2013. 31:433–41. doi:10.1007/s00774-013-0427-z 23420299 | Intervention/Exposure; Publication Date
107 | Okubo, H, Sasaki, S, Horiguchi, H, Oguma, E, Miyamoto, K, Hosoi, Y, Kim, MK, Kayama, F. Dietary patterns associated with bone mineral density in premenopausal Japanese farmwomen. American Journal of Clinical Nutrition. 2006. 83:1185–1192. | Outcome; Publication Date
108 | Orchard, T, Yildiz, V, Steck, SE, Hebert, JR, Ma, Y, Cauley, JA, Li, W, Mossavar-Rahmani, Y, Johnson, KC, Sattari, M, LeBoff, M, Wactawski-Wende, J, Jackson, RD. Dietary Inflammatory Index, Bone Mineral Density, and Risk of Fracture in Postmenopausal Women: Results From the Women’s Health Initiative. J Bone Miner Res. 2017. 32:1136–1146. doi:10.1002/jbmr.3070 28019686 | Intervention/Exposure
109 | Park, SJ, Joo, SE, Min, H, Park, JK, Kim, Y, Kim, SS, Ahn, Y. Dietary Patterns and Osteoporosis Risk in Postmenopausal Korean Women. Osong Public Health and Research Perspectives. 2012. 3:199–205. doi:10.1016/j.phrp.2012.10.005 24159515 | Publication Date
110 | Patel, A, Pyzik, PL, Turner, Z, Rubenstein, JE, Kossoff, EH. Long-term outcomes of children treated with the ketogenic diet in the past. Epilepsia. 2010. 51:1277–1282. doi:10.1111/j.1528-1167.2009.02488.x 20132287 | Health Status
111 | Pedone, C, Napoli, N, Pozzilli, P, Lauretani, F, Bandinelli, S, Ferrucci, L, Antonelli-Incalzi, R. Quality of diet and potential renal acid load as risk factors for reduced bone density in elderly women. Bone. 2010. 46:1063–1067. doi:10.1016/j.bone.2009.11.031 20005315 | Intervention/Exposure
112 | Pedone, C, Napoli, N, Pozzilli, P, Rossi, FF, Lauretani, F, Bandinelli, S, Ferrucci, L, Antonelli-Incalzi, R. Dietary pattern and bone density changes in elderly women: a longitudinal study. J Am Coll Nutr. 2011. 30:149–54. doi:10.1080/07315724.2011.10719954 21730223 | Publication Date
113 | Perez-Rey, J, Roncero-Martin, R, Rico-Martin, S, Rey-Sanchez, P, Pedrera-Zamorano, JD, Pedrera-Canal, M, Lopez-Espuela, F, Lavado Garcia, JM. Adherence to a Mediterranean Diet and Bone Mineral Density in Spanish Premenopausal Women. Nutrients. 2019. 11. doi:10.3390/nu11030555 | Study Design
114 | Petersen, SB, Rasmussen, MA, Olsen, SF, Vestergaard, P, Molgaard, C, Halldorsson, TI, Strom, M. Maternal dietary patterns during pregnancy in relation to offspring forearm fractures: prospective study from the Danish National Birth Cohort. Nutrients. 2015. 7:2382–400. doi:10.3390/nu7042382 25849947 | Intervention/Exposure; Age at Intervention or Exposure
115 | Promislow, JH, Goodman-Gruen, D, Slymen, DJ, Barrett-Connor, E. Protein consumption and bone mineral density in the elderly: the Rancho Bernardo Study. Am J Epidemiol. 2002. 155:636–44. doi:10.1093/aje/155.7.636 11914191 | Intervention/Exposure
116 | Reddy, ST, Wang, CY, Sakhaee, K, Brinkley, L, Pak, CY. Effect of low-carbohydrate high-protein diets on acid-base balance, stone-forming propensity, and calcium metabolism. Am J Kidney Dis. 2002. 40:265–74. doi:10.1053/ajkd.2002.34504 12148098 | Intervention/Exposure
117 | Rivas, A, Romero, A, Mariscal-Arcas, M, Monteagudo, C, Feriche, B, Lorenzo, ML, Olea, F. Mediterranean diet and bone mineral density in two age groups of women. Int J Food Sci Nutr. 2013. 64:155–61. doi:10.3109/09637486.2012.718743 22946650 | Publication Date
118 | Rogers, TS, Harrison, S, Judd, S, Orwoll, ES, Marshall, LM, Shannon, J, Langsetmo, L, Lane, NE, Shikany, JM. Dietary patterns and longitudinal change in hip bone mineral density among older men. Osteoporos Int. 2018. 29:1135–1145. doi:10.1007/s00198-018-4388-x 29450584 | Outcome
119 | Romera Baures, M, Morales Ivorra, I. Mediterranean diet and osteoarthritis. Reumatologia Clinica. 2019. 15:125–126. doi:10.1016/j.reuma.2018.12.001 30611670 | Outcome
120 | Roughead, ZK, Hunt, JR, Johnson, LK, Badger, TM, Lykken, GI. Controlled substitution of soy protein for meat protein: effects on calcium retention, bone, and cardiovascular health indices in postmenopausal women. J Clin Endocrinol Metab. 2005. 90:181–9. doi:10.1210/jc.2004-0393 15483071 | Intervention/Exposure; Publication Date
121 | Roughead, ZK, Johnson, LK, Lykken, GI, Hunt, JR. Controlled high meat diets do not affect calcium retention or indices of bone status in healthy postmenopausal women. J Nutr. 2003. 133:1020–6. doi:10.1093/jn/133.4.1020 12672913 | Intervention/Exposure; Publication Date
122 | Sahni, S, Cupples, LA, McLean, RR, Tucker, KL, Broe, KE, Kiel, DP, Hannan, MT. Protective effect of high protein and calcium intake on the risk of hip fracture in the Framingham offspring cohort. J Bone Miner Res. 2010. 25:2770–6. doi:10.1002/jbmr.194 20662074 | Intervention/Exposure; Publication Date
123 | Savanelli, MC, Barrea, L, Macchia, PE, Savastano, S, Falco, A, Renzullo, A, Scarano, E, Nettore, IC, Colao, A, Di Somma, C. Preliminary results demonstrating the impact of Mediterranean diet on bone health. J Transl Med. 2017. 15:81. doi:10.1186/s12967-017-1184-x 28438173 | Study Design
124 | Sellmeyer, DE, Stone, KL, Sebastian, A, Cummings, SR. A high ratio of dietary animal to vegetable protein increases the rate of bone loss and the risk of fracture in postmenopausal women. Study of Osteoporotic Fractures Research Group. Am J Clin Nutr. 2001. 73:118–22. doi:10.1093/ajcn/73.1.118 11124760 | Intervention/Exposure
125 | Sellmeyer, DE, Stone, KL, Sebastian, A, Cummings, SR. A high ratio of dietary animal to vegetable protein increases the rate of bone loss and the risk of fracture in postmenopausal women. American Journal of Clinical Nutrition. 2001. 73:118–122. | Publication Date
126 | Shaw, SC, Parsons, CM, Fuggle, NR, Edwards, MH, Robinson, SM, Dennison, EM, Cooper, C, Ward, KA. Diet Quality and Bone Measurements Using HRpQCT and pQCT in Older Community-Dwelling Adults from the Hertfordshire Cohort Study. Calcif Tissue Int. 2018. 103:494–500. doi:10.1007/s00223-018-0445-x 29931462 | Outcome
127 | Shin, S, Kim, SH, Joung, H, Park, MJ. Milk-cereal and whole-grain dietary patterns protect against low bone mineral density among male adolescents and young adults. Eur J Clin Nutr. 2017. 71:1101–1107. doi:10.1038/ejcn.2017.81 28561037 | Study Design
128 | Shin, S, Sung, J, Joung, H. A fruit, milk and whole grain dietary pattern is positively associated with bone mineral density in Korean healthy adults. Eur J Clin Nutr. 2015. 69:442–8. doi:10.1038/ejcn.2014.231 25351648 | Study Design
129 | Simm, PJ, Bicknell-Royle, J, Lawrie, J, Nation, J, Draffin, K, Stewart, KG, Cameron, FJ, Scheffer, IE, Mackay, MT. The effect of the ketogenic diet on the developing skeleton. Epilepsy Res. 2017. 136:62–66. doi:10.1016/j.eplepsyres.2017.07.014 28778055 | Health Status
130 | Skov, AR, Haulrik, N, Toubro, S, Molgaard, C, Astrup, A. Effect of protein intake on bone mineralization during weight loss: a 6-month trial. Obes Res. 2002. 10:432–8. doi:10.1038/oby.2002.60 12055318 | Intervention/Exposure
131 | Steell, L, Sillars, A, Welsh, P, Iliodromiti, S, Wong, SC, Pell, JP, Sattar, N, Gill, JMR, Celis-Morales, CA, Gray, SR. Associations of dietary protein intake with bone mineral density: An observational study in 70,215 UK Biobank participants. Bone. 2019. 120:38–43. doi:10.1016/j.bone.2018.10.003 30292817 | Study Design; Intervention/Exposure
132 | Subramonian, SS, Parker, AJP, Champion, HC. Bone health in Ketogenic diet therapy. Developmental medicine and child neurology. 2019. 61:88-. doi:10.1111/dmcn.14120 | Intervention/Exposure; Health Status
133 | Sukumar, D, Ambia-Sobhan, H, Zurfluh, R, Schlussel, Y, Stahl, TJ, Gordon, CL, Shapses, SA. Areal and volumetric bone mineral density and geometry at two levels of protein intake during caloric restriction: a randomized, controlled trial. J Bone Miner Res. 2011. 26:1339–48. doi:10.1002/jbmr.318 21611972 | Intervention/Exposure; Publication Date
134 | Svedlund, A, Hallbook, T, Magnusson, P, Dahlgren, J, Swolin-Eide, D. Prospective study of growth and bone mass in Swedish children treated with the modified Atkins diet. Eur J Paediatr Neurol. 2019. 23:629–638. doi:10.1016/j.ejpn.2019.04.001 31085021 | Country; Health Status
135 | Swanenburg, J, de Bruin, ED, Stauffacher, M, Mulder, T, Uebelhart, D. Effects of exercise and nutrition on postural balance and risk of falling in elderly people with decreased bone mineral density: randomized controlled trial pilot study. Clin Rehabil. 2007. 21:523–34. doi:10.1177/0269215507075206 17613583 | Intervention/Exposure
136 | Tang, M, Leidy, HJ, Campbell, WW. Regional, but not total, body composition changes in overweight and obese adults consuming a higher protein, energy-restricted diet are sex specific. Nutr Res. 2013. 33:629–35. doi:10.1016/j.nutres.2013.05.012 23890352 | Intervention/Exposure; Publication Date
137 | Thorpe, DL, Knutsen, SF, Beeson, WL, Rajaram, S, Fraser, GE. Effects of meat consumption and vegetarian diet on risk of wrist fracture over 25 years in a cohort of peri- and postmenopausal women. Public Health Nutr. 2008. 11:564–72. doi:10.1017/s1368980007000808 17686206 | Publication Date
138 | Thorpe, M, Mojtahedi, MC, Chapman-Novakofski, K, McAuley, E, Evans, EM. A positive association of lumbar spine bone mineral density with dietary protein is suppressed by a negative association with protein sulfur. J Nutr. 2008. 138:80–5. doi:10.1093/jn/138.1.80 18156408 | Intervention/Exposure
139 | Thorpe, MP, Jacobson, EH, Layman, DK, He, X, Kris-Etherton, PM, Evans, EM. A diet high in protein, dairy, and calcium attenuates bone loss over twelve months of weight loss and maintenance relative to a conventional high-carbohydrate diet in adults. J Nutr. 2008. 138:1096–100. doi:10.1093/jn/138.6.1096 18492840 | Publication Date
140 | Thorpe, MP, Mojtahedi, MC, Richey, AL, Layman, DK, Evans, EM. Higher protein weight loss diet does not affect bone mineral density (BMD) in a double-blind RCT in postmenopausal women. FASEB journal. 2010. 24. | Intervention/Exposure; Publication Status
141 | Tirosh, A, Carey, V, Sacks, F, Bray, G, Smith, SR, Leboff, M. The effect of weight loss and dietary macronutrient composition on bone mineral density-results of a randomized controlled trial. Journal of bone and mineral research. 2011. 26. | Intervention/Exposure; Publication Status
142 | Tucker, KL, Chen, H, Hannan, MT, Cupples, LA, Wilson, PW, Felson, D, Kiel, DP. Bone mineral density and dietary patterns in older adults: the Framingham Osteoporosis Study. Am J Clin Nutr. 2002. 76:245–52. doi:10.1093/ajcn/76.1.245 12081842 | Publication Date
143 | van den Hooven, EH, Ambrosini, GL, Huang, RC, Mountain, J, Straker, L, Walsh, JP, Zhu, K, Oddy, WH. Identification of a dietary pattern prospectively associated with bone mass in Australian young adults. Am J Clin Nutr. 2015. 102:1035–43. doi:10.3945/ajcn.115.110502 26377163 | Outcome
144 | van den Hooven, EH, Heppe, DH, Kiefte-de Jong, JC, Medina-Gomez, C, Moll, HA, Hofman, A, Jaddoe, VW, Rivadeneira, F, Franco, OH. Infant dietary patterns and bone mass in childhood: the Generation R Study. Osteoporos Int. 2015. 26:1595–604. doi:10.1007/s00198-015-3033-1 25792489 | Age at Intervention or Exposure
145 | Vatanparast, H, Bailey, DA, Baxter-Jones, AD, Whiting, SJ. The effects of dietary protein on bone mineral mass in young adults may be modulated by adolescent calcium intake. J Nutr. 2007. 137:2674–9. doi:10.1093/jn/137.12.2674 18029482 | Intervention/Exposure
146 | Veronese, N, Stubbs, B, Koyanagi, A, Hebert, JR, Cooper, C, Caruso, MG, Guglielmi, G, Reginster, JY, Rizzoli, R, Maggi, S, Shivappa, N. Pro-inflammatory dietary pattern is associated with fractures in women: an eight-year longitudinal cohort study. Osteoporos Int. 2018. 29:143–151. doi:10.1007/s00198-017-4251-5 29018920 | Intervention/Exposure
147 | Vuolo, L, Barrea, L, Savanelli, MC, Savastano, S, Rubino, M, Scarano, E, Soprano, M, Illario, M, Colao, A, Di Somma, C. Nutrition and Osteoporosis: Preliminary data of Campania Region of European PERsonalised ICT Supported Service for Independent Living and Active Ageing. Transl Med UniSa. 2015. 13:13–8.27042428 | Study Design
148 | Ward, KA, Prentice, A, Kuh, DL, Adams, JE, Ambrosini, GL. Life Course Dietary Patterns and Bone Health in Later Life in a British Birth Cohort Study. J Bone Miner Res. 2016. 31:1167–76. doi:10.1002/jbmr.2798 26817442 | Outcome
149 | Weaver, AA, Houston, DK, Shapses, SA, Lyles, MF, Henderson, RM, Beavers, DP, Baker, AC, Beavers, KM. Effect of a hypocaloric, nutritionally complete, higher-protein meal plan on bone density and quality in older adults with obesity: a randomized trial. Am J Clin Nutr. 2019. 109:478–486. doi:10.1093/ajcn/nqy237 30624598 | Intervention/Exposure; Comparator
150 | Weikert, C, Walter, D, Hoffmann, K, Kroke, A, Bergmann, MM, Boeing, H. The relation between dietary protein, calcium and bone health in women: results from the EPIC-Potsdam cohort. Ann Nutr Metab. 2005. 49:312–8. doi:10.1159/000087335 16088096 | Intervention/Exposure; Publication Date
151 | Wosje, KS, Khoury, PR, Claytor, RP, Copeland, KA, Hornung, RW, Daniels, SR, Kalkwarf, HJ. Dietary patterns associated with fat and bone mass in young children. Am J Clin Nutr. 2010. 92:294–303. doi:10.3945/ajcn.2009.28925 20519562 | Publication Date
152 | Wright, C, Zhou, J, Campbell, W. Increased milk protein isolate consumption during diet-induced energy restriction does not influence changes in bone quantity in overweight and obese older adults. Journal of bone and mineral research. 2017. 31. doi:10.1002/jbmr.3107 | Intervention/Exposure
153 | Yang, TC, Aucott, LS, Duthie, GG, Macdonald, HM. An application of partial least squares for identifying dietary patterns in bone health. Arch Osteoporos. 2017. 12:63. doi:10.1007/s11657-017-0355-y 28702941 | Study Design
154 | Yildiz, V, Steck, S, Hebert, J, Jackson, R. Association of the Dietary Inflammatory Index, bone mineral density and risk of fracture in postmenopausal women. Journal of bone and mineral research. Conference: 2015 annual meeting of the american society for bone and mineral research, ASBMR 2015. United states. 2015. 30. doi:10.1002/jbmr.2763 | Intervention/Exposure
155 | Zhang, Q, Ma, G, Greenfield, H, Zhu, K, Du, X, Foo, LH, Hu, X, Fraser, DR. The association between dietary protein intake and bone mass accretion in pubertal girls with low calcium intakes. Br J Nutr. 2010. 103:714–23. doi:10.1017/s0007114509992303 19814838 | Intervention/Exposure
156 | Zhang, X, Shu, XO, Li, H, Yang, G, Li, Q, Gao, YT, Zheng, W. Prospective cohort study of soy food consumption and risk of bone fracture among postmenopausal women. Arch Intern Med. 2005. 165:1890–5. doi:10.1001/archinte.165.16.1890 16157834 | Intervention/Exposure

ix Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

x Intermediate outcomes were included for all study designs in children and intervention studies in adults.

xi The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).