# WHAT IS THE RELATIONSHIP BETWEEN DIETARY PATTERNS CONSUMED AND BONE HEALTH?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between dietary patterns consumed and bone health?

### What is the answer to the question?

- Moderate evidence indicates that a dietary pattern higher in fruits, vegetables, legumes, nuts, low-fat dairy, whole grains, and fish, and lower in meats (particularly processed meats), sugar sweetened beverages, and sweets is associated with favorable bone health outcomes in adults, primarily decreased risk of hip fracture.
- Insufficient evidence is available to determine the relationship between dietary patterns consumed during childhood and bone health.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Dietary Patterns Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.

### What is the population of interest?

- Children and adults, ages 2 years and older

### What evidence was found?

- This review update includes 9 studies: 7 in adults and 2 in children/adolescents.
- Children/adolescents:
  ○ The 2020 Committee could not draw a conclusion due to limitations in and lack of evidence.
- Adults:
  ○ Dietary patterns consumed by adults were associated with favorable bone health in most studies. These dietary patterns were higher in fruits, vegetables, legumes, nuts, low-fat dairy, whole grains, and fish, and lower in meats, sugar sweetened beverages, and sweets.
  ○ Key limitations in study design and conduct of the included articles were identified. This includes not accounting for potential confounders or changes in diet over time, and missing or incomplete data.
  ○ The 2020 Committee updates and strengthens the conclusion drawn by the 2015 Committee.

### How up-to-date is this systematic review?

- The update to the existing review searched for studies published from January, 2014 to November, 2019, and updated an existing systematic review that included evidence from January, 2000 to January, 2014.

## FULL REVIEW

### Systematic review question

What is the relationship between dietary patterns consumed and bone health?

### Conclusion statements and grades

Moderate evidence indicates that a dietary pattern higher in fruits, vegetables, legumes, nuts, low-fat dairy, whole grains, and fish, and lower in meats (particularly processed meats), sugar sweetened beverages, and sweets is associated with favorable bone health outcomes in adults, primarily decreased risk of hip fracture. (Grade: Adults – Moderate)

Insufficient evidence is available to determine the relationship between dietary patterns consumed during childhood and bone health. (Grade: Children – Grade not assignable)

### Summary of the evidence

- This systematic review update includes nine prospective cohort studies (PCSs) that examined the relationship between dietary patterns and bone health, met inclusion criteria, and were published between January 2014 and November 2019.
  ○ Seven studies examined dietary patterns consumed by adults and bone health in older adults.^1–7^
  ○ Two articles from the same study were conducted that examined dietary patterns consumed by children and adolescents and bone health outcomes after a 4-year follow-up (approximately age 17 years).^8,9^
- The direction and magnitude of effect across the body of evidence was consistent, pointing to healthier dietary patterns leading to a reduced risk of hip fractures. The studies in adults had large analytic sample sizes with a sufficient number of hip fracture cases occurring over follow-up to examine associations. Although the search strategy included other bone health outcomes, the eligible studies looked only at fractures (mainly hip) and forearm bone mineral density (in adolescents).
- The body of evidence consistently had risks of bias, including lack of adjustment for all potential confounders and a lack of accounting for possible changes in dietary intake that may have occurred over follow-up.
- This systematic review updates and builds upon an existing systematic review from the 2015 Dietary Guidelines Advisory Committee,.^ii^ which previously determined that limited evidence suggests a relationship between dietary patterns and bone health in adults. In that previous review, a grade was not assignable in children and adolescents due to limited evidence from a small number of studies with wide variation in study design, dietary assessment methodology, and bone health outcomes.
  ○ Based on the 7 additional studies in this update to the existing review examining dietary patterns consumed by adults, moderate evidence is now available to indicate a significant relationship between dietary patterns and risk of hip fracture in older adults.
  ○ Based on the 2 additional studies in this update to the existing review examining dietary patterns consumed by children or adolescents, no change is warranted in the level of evidence to evaluate the relationship between dietary patterns and bone health in children.
  ○ Although the number of recent studies is modest, they are consistent in how dietary intake was evaluated, in magnitude of effect reported, and in evaluated outcomes

### Description of the evidence

This systematic review update includes seven PCSs in adults^1–7^ and two PCSs in adolescents^8,9^ that examined the relationship between dietary patterns and bone health, met inclusion criteria, and were published between January 2014 and November 2019.

#### Population/participant characteristics

The studies included in this systematic review were conducted in Sweden,^2,7^ the Netherlands,^3^ the United States,^4–6^ Portugal,^8,9^ and one study spanning four different cohorts in three countries (Greece, Sweden and the United States).^1^ Three studies contain data from the same cohort in Sweden^1,2,7^ but examined different dietary patterns in relation to bone health (hip fracture). Sample size of the studies was large for adults, ranging from 4,028 to 140,775 participants and relatively smaller in adolescents, ranging from 1,007 to 1,023 participants. The adult studies enrolled older participants, and mean age of participants at baseline ranged from approximately 53 years to 66 years. The papers in adolescents had a mean age at baseline of 13 years.^8,9^

A few studies excluded participants with a previous hip fracture^1,4,5^ or with history of cancer at baseline^2,4,5,7^ and one excluded those with a history of cardiovascular disease at baseline.^2^ Despite these exclusions, studies included participants who were reflective of the general population (e.g., healthy and/or at risk of chronic disease, or diagnosed with a chronic disease).

#### Intervention/exposure

Included studies examined dietary patterns using a variety of methods. Four studies examined adherence to dietary patterns using different indices or scores.^1,2,5,6^ Two studies examined patterns by factor and cluster analysis,^4,7^ and one study identified dietary patterns using reduced rank regression.^3^ For the two papers in adolescents, one utilized indices or scores^8^ and the other analyzed patterns with a factor and cluster analysis.^9^

Dietary intake was assessed using validated food frequency questionnaires (FFQs) in all studies. Most studies assessed diet once at baseline,^1–3,6^ though one study collected 2 FFQs during follow-up,^7^ and two studies evaluated diet by collecting FFQs multiple times during the period of long follow-up.^4,5^ Both adolescent studies assessed dietary intake once at baseline using an FFQ.^8,9^

#### Outcome assessment

All included adult studies examined risk of hip fracture, with follow-up ranging from 13 to 32 years. In addition to evaluating risk of hip fractures, one study evaluated osteoporotic fractures,^3^ and one looked at total fracture risk.^6^ No studies that met inclusion criteria examined intermediate outcomes (e.g., bone mineral density) in adults, osteoporosis, or rickets. Both studies conducted in adolescents focused on bone mineral density (BMD).^8,9^

### Evidence synthesis

#### Description of the results

Results reported by the included studies examining dietary patterns consumed by adults were consistent overall (Table 1). Byberg et al^2^ reported that for Swedish adults that scored higher on the modified Mediterranean diet (mMED) score at mean age 60 years, their risk of hip fracture was lower after up to 15 years of follow-up. Similarly, Fung et al^5^ found that better adherence to the Alternative Healthy Eating Index – 2010 (AHEI-2010) index resulted in reduced risk of hip fracture in women age 55 years, after about 32 years of follow-up. When stratifying by age in this same study, there was a significant reduction in risk of hip fracture with higher adherence to the AHEI-2010, alternate Mediterranean diet score (aMED), and Dietary Approaches to Stop Hypertension (DASH) scores in women under age 75 years.^5^ However, there were no significant associations between the three scores (AHEI-2010, aMED, DASH) and hip fracture risk in men regardless of age stratification.^5^ There was also a significant relationship between a higher aMED score and reduced hip fracture risk in Haring et al,^6^ in women age 64 years over a 16 year follow-up.

Fung and Feskanich^4^ identified two dietary patterns using factor analysis (“prudent” and “western”), but found no significant association between adherence to these patterns and risk of hip fracture or total fracture. Similar patterns (“healthy” and “western”) were identified through factor analysis by Warensjo Lemming et al^7^ and greater adherence to the “healthy pattern” was significantly associated with a reduced risk of hip fracture at age 53 years after 25 years of follow-up, whereas, better adherence to the “western pattern” was associated with higher hip fracture risk. Of the dietary patterns determined by reduced rank regression by De Jonge et al,^3^ only one (“sweets, animal fat, and low meat pattern”) was inversely associated with risk of osteoporotic fractures and hip fractures. The “fruit, vegetables, and dairy pattern” was not significantly associated with risk of hip or osteoporotic fractures at age 66 years after up to 15 years of follow-up.^3^

In the study that evaluated adherence to the modified Mediterranean diet score (mMDS) in five different cohorts separately^1^ in Greece, Sweden and the United States only in the Swedish Mammography Cohort was an increased mMDS score found to reduce hip fracture risk. There were no significant associations in the other four cohorts (EPIC-Elderly Greece, EPIC-Elderly Umea, Cohort of Swedish Men, and the Nurses’ Health Study) with mMDS adherence and hip fracture risk.

Of the two studies conducted in adolescents, the first^8^ found no significant association between adherence to the Mediterranean Diet Quality Index for Children and Adolescents (KIDMED) or DASH score at age 13 years and BMD changes during a 4 year follow-up in girls and boys. Factor analysis was used in the second study^9^ to identify four dietary patterns. Results showed that greater adherence to a “lower intake” pattern compared to a “healthier” pattern was significantly associated with reduced BMD annually over four years in girls, but not boys. There was no significant association between the “dairy products” pattern or “fast food and sweets” pattern compared to a “healthier” pattern and annual changes in BMD in boys or girls.

#### Assessment of the evidence^iii^

This systematic review update included seven studies that examined dietary patterns consumed by adults and two studies that examined dietary patterns consumed during childhood/adolescence that met inclusion criteria, and all were prospective cohort observational studies. The studies were variable in duration of follow-up and although a variety of patterns were assessed, included components were similar across the studies. There was consistency in how dietary intake was evaluated, in magnitude of effect of reported results, direction of results, and in evaluated outcomes. Based on this assessment, a conclusion was drawn indicating that moderate evidence suggests a significant association between dietary patterns consumed by adults and bone health (primarily hip fracture risk).

Multiple databases were used to obtain publications from a large, comprehensive search. Studies with varying sample sizes were included. Therefore, this risk of publication bias is low. As outlined and described below, the body of evidence was assessed for the following elements used when grading the strength of evidence.

- Risk of bias: The included studies had a number of potential risks of bias that may have influenced study results (Table 1, Table 2). While studies accounted for a number of potential confounders, they did not account for all key confounders, such as race/ethnicity, socioeconomic status, and vitamin D status. All studies examined dietary patterns at least once (at baseline), however, over half of studies in adults did not account for possible changes in dietary intake that may have occurred over follow-up. In addition, aside from the papers conducted in adolescents, the studies primarily enrolled older individuals, and did not account for dietary patterns consumed or variability of consumption earlier in life. There was inconsistency across studies with regards to accounting for missing data and data on non-completers, either from participants that were lost to follow-up or criteria used when selecting participants into the analyses. Finally, because these were all observational studies, often with decades long follow-ups, published analytic plans were not available for any of the included articles, and therefore, the risk is unclear of potential a priori analytical plans and/or selective outcome reporting.
- Consistency: The direction and magnitude of effect across the body of evidence were mostly consistent. The majority of studies reported at least one significant association between adherence to a dietary pattern and risk of hip fracture (or bone mineral density in adolescents). In general, healthier patterns led to a significant reduction in hip fracture risk and those patterns classified as less healthy were significantly associated with increased risk of hip fracture. Magnitude of these effects was consistent. However, these results were not always consistent by gender or age group. There were also multiple patterns that yielded insignificant results for changes in bone health outcomes.
- Directness: The populations, intervention, comparators, and outcomes of interest in the included studies are directly related to the systematic review question.
- Precision: Power analyses or sample size calculations were not reported in the included studies, which were all observational. However, the majority had large analytic sample sizes with a large number of fracture cases occurring during follow-up. Sample sizes were considerably smaller in the two studies conducted in adolescents, but both still had over 1000 participants. The width of confidence intervals were narrow, pointing to a degree of precision within the body of evidence.
  Generalizability: The study participants, exposures, comparators, and outcomes examined in the body of evidence may be generalizable to the adult U.S. population overall due to a large proportion of the participants being from the U.S. and populations similar to the U.S., e.g., Sweden, Greece, Netherlands. Whereas, the studies addressing children were exclusively from Portugal which may limit generalizability to the U.S.

This systematic review updates the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee.^iv^ The 2015 Advisory Committee concluded that, “Limited evidence suggests that a dietary pattern higher in vegetables, fruits, grains, nuts, and dairy products, and lower in meats and saturated fat, is associated with more favorable bone health outcomes in adults, including decreased risk of fracture and osteoporosis, as well as improved bone mineral density. Although a growing number of studies are examining the relationship between dietary patterns and bone health in adults, the number of high-quality studies is modest and those available employ a wide range of methodologies in study design, dietary assessment techniques, and varying bone health outcomes. (Grade: Limited).” In that previous review, a grade was not assignable in children and adolescents due to limited evidence from a small number of studies with wide variation in study design, dietary assessment methodology and bone health outcomes. These conclusions were based on 2 RCTs and 11 PCSs published between 2000 and 2014. In this update on papers published between 2014 and 2019, there are 7 additional studies examining dietary patterns consumed by adults that show there is now moderate evidence to suggest that there is a significant relationship between dietary patterns and risk of hip fracture in adults. Based on the 2 additional studies in this update to the existing review examining dietary patterns consumed by children or adolescents, there is no change in the strength of evidence available to evaluate the relationship between dietary patterns and bone health in children or adolescents.

### Research recommendations

In order to better assess the relationship between dietary patterns and bone health, future research may:

1. Examine dietary patterns more comprehensively with a broader group of bone health outcomes, i.e., osteoporosis, osteopenia, rickets, and broader fractures (in addition to hip fractures)
2. Include diverse populations varying not only by race/ethnicity, but also by age (i.e., children, adolescents, and young adults), socioeconomic background, and health status.
3. Explore the role of dietary fiber and other individual elements within dietary patterns beyond sources of calcium and vitamin D that might be contributing to the association between dietary patterns and bone health
4. Consider the role of vitamin D in the relationship between dietary patterns and bone health, as the current review is lacking this information (as either a mediator or confounder) in the causal pathway.
5. Evaluate additional factors that might increase bone health risk and influence the dietary pattern in order to inform analytic plans and data collection
6. Examine broader dietary patterns inclusive of foods associated with positive bone health and negatively associated with bone health.

### Included articles

1 Benetou V, Orfanos P, Feskanich D, . Mediterranean diet and hip fracture incidence among older adults: the CHANCES project. Osteoporos Int. 2018;29(7):1591–1599. doi:10.1007/s00198-018-4517-6.29656347
2 Byberg L, Bellavia A, Larsson SC, Orsini N, Wolk A, Michaelsson K. Mediterranean diet and hip fracture in Swedish men and women. J Bone Miner Res. 2016;31(12):2098–2105. doi:10.1002/jbmr.2896.27345330
3 de Jonge EA, Kiefte-de Jong JC, Hofman A, . Dietary patterns explaining differences in bone mineral density and hip structure in the elderly: the Rotterdam Study. Am J Clin Nutr. 2017;105(1):203–211. doi:10.3945/ajcn.116.139196.27903522
4 Fung TT, Feskanich D. Dietary patterns and risk of hip fractures in postmenopausal women and men over 50 years. Osteoporos Int. 2015;26(6):1825–1830. doi:10.1007/s00198-015-3081-6.25731807
5 Fung TT, Meyer HE, Willett WC, Feskanich D. Association between diet quality scores and risk of hip fracture in postmenopausal women and men aged 50 years and older. J Acad Nutr Diet. 2018;118(12):2269–2279.e2264. doi:10.1016/j.jand.2017.11.022.29398568
6 Haring B, Crandall CJ, Wu C, . Dietary patterns and fractures in postmenopausal women: results from the Women’s Health Initiative. JAMA Intern Med. 2016;176(5):645–652. doi:10.1001/jamainternmed.2016.0482.27019044
7 Warensjo Lemming E, Byberg L, Melhus H, Wolk A, Michaelsson K. Long-term a posteriori dietary patterns and risk of hip fractures in a cohort of women. Eur J Epidemiol. 2017;32(7):605–616. doi:10.1007/s10654-017-0267-6.28585122
8 Monjardino T, Lucas R, Ramos E, Barros H. Associations between a priori-defined dietary patterns and longitudinal changes in bone mineral density in adolescents. Public Health Nutr. 2014;17(1):195–205. doi:10.1017/s1368980012004879.23149164
9 Monjardino T, Lucas R, Ramos E, Lopes C, Gaio R, Barros H. Associations between a posteriori defined dietary patterns and bone mineral density in adolescents. Eur J Nutr. 2015;54(2):273–282. doi:10.1007/s00394-014-0708-x.24806081

Table 1 Description of studies that examined the relationship between dietary patterns and bone health^v^

Study and Participant Characteristics.^vi^ | Dietary Pattern | Results | Methodological Considerations
Benetou, 2018 ^1^; Greece, Sweden, United States EPIC-Elderly Greece, EPIC-Elderly Umea, Cohort of Swedish Men (COSM), Swedish Mammography Cohort (SMC), Nurse’s Health Study (NHS); Prospective Cohort Studies; N=140,775 (N=9,534 for EPIC-Elderly Greece, N=3,276 for EPIC-Elderly Umea, N=19,240 for COSM, N=17,173 for SMC, N=91,552 for NHS); 83% female (60% female for EPIC-Elderly Greece, 53% female for EPIC-Elderly Umea, 0% female for COSM, 100% female for SMC and NHS), excluded those with a previous hip fracture or data missing on hip fracture in f/u | Index/Score:; Modified Mediterranean diet score (mMDS) components:; - Vegetables, legumes, fruits, cereals, fish, meat and dairy products, monounsaturated lipids, ethanol (excluded nuts) | EPIC-Elderly Greece; - Hip fracture risk at f/u: NS; EPIC-Elderly Umea; - Hip fracture risk at f/u: NS; COSM; - Hip fracture risk at f/u: NS; SMC (HR, 95% CI); - Hip fracture risk at f/u: 0.93 (0.88, 0.98); NHS; - Hip fracture risk at f/u: NS | Key confounders accounted for:; Sex; Age; Marital status, Education; BMI, height; Smoking; Alcohol; Physical activity; Other: Energy intake, history of comorbidity; Limitations:; - Did not account for: race/ethnicity, vitamin D status, calcium supplements, estrogen replacement therapy; - Diet assessed only once at baseline; - No information on non-completers; - No preregistered data analysis plan
Byberg, 2016 ^2^; Sweden, Cohort of Swedish Men and Swedish Mammography Cohort; Prospective Cohort Study; N=71,333; 47% female, 60y, excluded those with missing data, CVD or cancer before baseline | Index/score:; Modified Mediterranean diet score (mMED) at 60y; - Positive components: Fruit and vegetables, legumes and nuts, non-refined or high-fiber grains, fermented dairy products, fish, use of olive or rapeseed oil; - Neutral components: Alcohol; - Negative components: Red and processed meat | mMED at 60y (categorical, continuous) and hip fracture after up to 15 y f/u (HR, 95% CI):; - 0–2 pts, n=749: HR: 1.00; - 3–5 pts, n=1,975: 0.88 (0.80, 0.96); - 6–8 pts, n=451: 0.78 (0.69, 0.89); Continuous (per pt increase), n=3,175: 0.94 (0.92, 0.96) | Key confounders accounted for:; Sex; Age; Education; BMI and height; Smoking; Alcohol intake; Physical activity; Vitamin D status (supplements and dietary intake); Calcium supplements and dietary intake; Other: Diabetes, living alone, total energy intake, retinol intake, Charlson comorbidity index; Limitations:; - Did not account for: race/ethnicity, estrogen replacement therapy; - Diet assessed only once at baseline; - No information on non-completers; - No preregistered data analysis plan
De Jonge, 2017 ^3^; The Netherlands, Rotterdam Study, Prospective Cohort Study; N=4,028; 53% female, 66y (>50y), excluded those with missing or unreliable data | Reduced rank regression:; - Four dietary patterns were identified using the following response variables: femoral neck bone mineral density, bone width, section modulus, and cortical bucking ratio. Only 2 that explained the most variance were used in this analysis.; - “Fruit, vegetables, and dairy” pattern: Higher loadings for fruits, vegetables, milk, yogurt, and lower loadings for sweets, animal fats; - “Sweets, animal fat, and low meat” pattern: Higher loadings for refined grains, sweets, animal fats, porridge, and lower loadings for soy, meat, poultry | “Fruit, vegetables, and dairy” pattern at 66y (continuous):; - Osteoporotic fractures at 13 y f/u: NS; - Hip fractures at 15 y f/u: NS; “Sweets, animal fat, and low meat” pattern at 66y (continuous) (HR, 95% CI):; - Osteoporotic fractures at 13 y f/u: 1.10, (1.06, 1.15), p<0.05; - Hip fractures at 15 y f/u: 1.10, (1.06, 1.15), p<0.05 | Key confounders accounted for:; Sex; Age; Education, Income; Body weight and height; Smoking; Physical activity; Vitamin D status; Estrogen replacement therapy; Other: Total energy intake, use of lipid-lowering drugs, type 2 diabetes, disability, age at menopause, anti-hypertensive drugs, bone mineral density/ width/ section modulus/ buckling ratio; Limitations:; - Did not account for: race/ethnicity, alcohol intake, calcium supplements; - Diet assessed only once at baseline; - No information on non-completers; - No preregistered data analysis plan
Fung, 2015 ^4^; United States, Nurses’ Health Study and Health Professionals Follow-up Study; Prospective Cohort Study; N=112,845; 66% female, ~55y (30-75y), excluded those with a previously reported hip fracture, diagnosis of cancer, diagnosed osteoporosis, or non-white race/ethnicity, missing dietary data | Factor/Cluster:; Two dietary patterns were identified:; - “Prudent”: characterized by higher intake of fruits, vegetables, whole grains, poultry, and low fat dairy products; “Western”: characterized by higher intake of red and processed meats, refined grains, sweets and desserts and full fat dairy products | “Prudent” pattern:; - Hip fracture at ~20 y f/u: NS; “Western” pattern:; - Hip fracture at ~20 y f/u: NS | Key confounders accounted for:; Age; Sex; BMI; Race/ethnicity; Smoking; Physical activity; Calcium supplements; Post-menopausal hormone use (women); Other: Energy intake, thiazides, lasix, anti-inflammatory steroids, multivitamin supplements; Limitations:; - Did not account for: socioeconomic status, vitamin D status; - A posteriori method usedto identify dietary patterns; - No information on non-completers; - No preregistered dataanalysis plan
Fung, 2018 ^5^; United States, Nurses’ Health Study and Health Professionals Follow-up Study; Prospective Cohort Study; N=111,048; 67% female, ~55y (30-75y), excluded those with a previously reported hip fracture, diagnosis of cancer, diagnosed osteoporosis, or non-white race/ethnicity | Index/Score:; Alternative Healthy Eating Index 2010 (AHEI-2010); - Positive components: vegetables, whole fruits, nuts and legumes, whole grains, polyunsaturated fat, and long chain n-3 fatty acids; - Negative components: red and processed meats, sugar sweetened beverages and fruit juice, trans fat, and sodium; alternate Mediterranean diet score (aMED); - Positive components: vegetables, fruits, whole grains, nuts, legumes, fish, monounsaturated-to-saturated fat ratio; - Negative components: Red and processed meat; Dietary Approaches to Stop Hypertension (DASH) score; - Positive components: fruits, vegetables, nuts and legumes, whole grains, and low-fat dairy products.; - Negative components: red and processed meats, sodium, and sugar sweetened beverages | [underlined: WOMEN]; AHEI-2010; - Hip fracture at ~32y f/u (RR, 95% CI):; ○ Q1, n=423: 1.00; ○ Q2, n=406: 1.00 (0.88, 1.14), NS; ○ Q3, n=390: 1.01 (0.89, 1.14), NS; ○ Q4, n=323: 0.93 (0.81, 1.06), NS; ○ Q5, n=316: 0.87 (0.75, 1.00); ○ p-trend=0.02; aMED; - Hip fracture at ~32y f/u: NS; DASH; - Hip fracture at ~32y f/u:; ○ Q1, n=333: 1.00; ○ Q2, n=471: 1.19 (1.03, 1.37); ○ Q3, n=468: 1.12 (0.96, 1.29), NS; ○ Q4, n=434: 0.99 (0.85, 1.15), NS; ○ Q5, n=437: 0.95 (0.81, 1.11), NS; ○ p-trend=0.03; - Stratified by age (< or >75y), hip fracture risk significantly decreased as all three scores increased in women <75y; [underlined: MEN]; AHEI-2010, aMED, DASH:; - Hip fracture at ~32y f/u: NS | Key confounders accounted for:; Age; Sex; BMI, height; Race/ethnicity; Smoking; Alcohol; Physical activity; Vitamin D status; Calcium supplements; Post-menopausal hormone use (women); Other: Thiazides, Lasix, anti-inflammatory steroids, multivitamins, retinol supplements, caffeine intake, sugar sweetened beverages (aMed), history of diabetes; Limitations:; - Did not account for: socioeconomic status; - No information on non-completers; - No preregistered data analysis plan
Haring, 2016 ^6^; United States, Women’s Health Initiative Observational Study; Prospective Cohort Study; N=90.014; 100% female, 64y (50-79y), excluded those with missing data, implausible energy intake | Index/score:; Healthy Eating Index 2010 (HEI-2010); - Positive components: Total vegetables, geens and beans, total fruit, whole fruit, whole grains, seafood and plant proteins, total protein foods, dairy, fatty acids; - Negative components: Refined grained, added sugars, solid fats, sodium; Alternative Healthy Eating Index 2010 (AHEI-2010); - Positive components: Vegetables (not potatoes, French fries), Fruit, Whole Grains, Long-Chain Fats (EPA + DHA), PUFA; - Neutral components: Alcohol; - Negative components: Red and Processed Meat, Sugar Sweetened Beverages and Fruit Juice, Trans FA, Sodium; alternate Mediterranean diet score (aMED); - Positive components: Vegetables (not potatoes), legumes, fruits, nuts, whole grains, fish, MUFA/SFAs; - Neutral components: Alcohol; - Negative components: Red and processed meat; Dietary Approaches to Stop Hypertension (DASH) score; - Positive components: Vegetables (not potatoes), nuts and legumes, fruit and fruit juice, whole grains, low-fat dairy; - Negative components: Red and processed meat, sweetened beverages, sodium | HEI-2010; - Hip fracture at 16y f/u: NS; - Total fracture at 16y f/u: NS; AHEI-2010; - Hip fracture at 16y f/u: NS; - Total fracture at 16y f/u: NS; aMED; - Hip fracture at 16y f/u (HR, 95% CI):; ○ Q1, n=177: 1.00; ○ Q2, n=680: 0.84 (0.70, 1.01); ○ Q3, n=396: 0.77 (0.63, 0.94); ○ Q4, n=366: 0.76 (0.62, 0.92); ○ Q5, n=502: 0.80 (0.66, 0.97); - Total fracture at 16y f/u: NS; DASH; - Hip fracture at 16y f/u: NS; Total fracture at 16y f/u: NS | Key confounders accounted for:; Sex; Age; Race/ethnicity; BMI; Smoking; Alcohol intake; Physical activity; Calcium supplements; Estrogen replacement therapy; Other: Diabetes status, history of fracture, physical function score, chronic medical conditions, psychoactive medications; Limitations:; - Did not account for: socioeconomic status, vitamin D status; - Diet assessed only once at baseline; - No preregistered data analysis plan
Monjardino, 2014 ^8^; Portugal, EPITeen Cohort; Prospective Cohort Study; N=1,023; 54% girls, 13y, excluded those with missing or implausible data | Index/Score:; Mediterranean Diet Quality Index for children and adolescents (KIDMED); - Positive components: fruit and vegetables, nuts, fish, pulses, pasta or rice, grains or cereals, dairy products, olive oil; - Negative components: sweets, candy, commercially baked goods, pastries, fast foods, and non-consumption of breakfast; DASH; - Positive components: fruit, vegetables, nuts, legumes, dairy products and whole grains; - Negative components: sodium, red and processed meat, sweetened beverages; Oslo Health Study dietary index (OHS); - A ratio between the intake of soft drinks and the intake of fruit/berries, fruit juice and cooked and raw vegetables | KIDMED; - Annual bone mineral density (BMD) variation at 4y f/u, NS; DASH; - Annual BMD variation at 4y f/u, NS; OHS:; - Annual BMD variation at 4y f/u, NS | Key confounders accounted for:; Sex; Age; Parent education; Height, weight; Physical activity; Calcium intake; Other: Energy intake, age at menarche (girls); Limitations:; - Did not account for: Race/ethnicity, Vitamin D status; - Diet assessed only once at baseline; - No information on non-completers; - No preregistered data analysis plan
Monjardino, 2015 ^9^; Portugal, EPITeen Cohort; Prospective Cohort Study; N=1,007; 54% girls, 13y, excluded those with missing or implausible data | Factor/Cluster:; Four dietary patterns identified:; - “Healthier” (ref): characterized by the highest consumption of fish, vegetables and added fats. High consumption of fruits and pasta/potatoes/rice and the lowest consumption of fast food and soft drinks; - “Dairy Products”: characterized by the highest consumption of dairy products and an intermediate consumption of most food groups; - “Fast food and sweets”: characterized by the highest energy intake and by the highest intake of sweets, fast food, soft drinks and coffee/tea; and “lower intake”: characterized by low intake of all food groups, particularly of red meat, fish, fruits, pasta/potatoes/rice, dairy products, cereals and added fats. | [underlined: GIRLS (coefficient, 95% CI)]; “Dairy Products” vs. “Healthier”; - Annual BMD variation at 4y f/u, NS; “Fast food and sweets” vs. “Healthier”; - Annual BMD variation at 4y f/u, NS; “Lower intake” vs. “Healthier”; - Annual BMD variation at 4y f/u: −0.451 (−0.827, −0.074); [underlined: BOYS]; “Dairy Products” vs. “Healthier”; - Annual BMD variation at 4y f/u, NS; “Fast food and sweets” vs. “Healthier”; - Annual BMD variation at 4y f/u, NS; “Lower intake” vs. “Healthier”; - Annual BMD variation at 4y f/u, NS | Key confounders accounted for:; Sex; Age; Height, weight; Other: Energy intake, age at menarche (girls); Limitations:; - Did not account for: Race/ethnicity, Vitamin D status, socioeconomic status, physical activity, calcium intake; - A posteriori method used to identify dietary patterns; - Diet assessed only once at baseline; - No information on non-completers; - No preregistered data analysis plan
Warensjo Lemming, 2017 ^7^; Sweden, Swedish Mammography Cohort; Prospective Cohort Study; N=56,736; 100% female, 53y, excluded those with missing data, history of cancer | Factor/cluster:; Two of four dietary patterns identified were analyzed:; - “Healthy” pattern: Higher loadings for fish (all types), cereals and whole meal bread, poultry, eggs, pasta and rice, fruits, vegetables, fermented milk,; - “Western/convenience” pattern: Higher loadings for sweet snacks and bakery products, sugar, jams, sodas, savoury snacks, meat, white bread | “Healthy” pattern at 53y and hip fracture after 25.5 y f/u (HR, 95% CI):; - Q1, n=1,501: 1.00; - Q2, n=1,304: 0.79 (0.73, 0.85); - Q3, n=1,190: 0.71 (0.66, 0.77); - Q4, n=1,002: 0.57 (0.52, 0.62); “Western/convenience” pattern at 53y and hip fracture after 25.5 y f/u:; - Q1, n=1,066: 1.00; - Q2, n=1,229: 1.17 (1.07, 1.27); - Q3, n=1,288: 1.17 (1.07, 1.27); - Q4, n=1,414: 1.22 (1.10, 1.34) | Key confounders accounted for:; Sex; Education; Height, BMI; Smoking; Alcohol intake; Physical activity; Calcium supplements; Other: Living alone, multivitamin use, previous fracture, menopausal status, Charlson’s comorbidity index, total energy intake; Limitations:; - Did not account for: age, vitamin D status, estrogen replacement therapy; - A posteriori method used to identify dietary patterns; - Diet assessed only once at baseline; - No information on non-completers; - No preregistered data analysis plan

Table 2 Risk of bias for observational studies examining dietary patterns and bone health^vii,^ ^viii^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Benetou, 2018 ^1^ | Serious | Moderate | Low | Serious | Moderate | Low | Moderate
Byberg, 2016 ^2^ | Serious | Moderate | Low | Serious | Serious | Low | Moderate
de Jonge, 2017 ^3^ | Serious | Moderate | Low | Serious | Serious | Low | Moderate
Fung, 2015 ^4^ | Serious | Moderate | Low | Moderate | Low | Low | Moderate
Fung, 2018 ^5^ | Serious | Moderate | Low | Moderate | Low | Low | Moderate
Haring, 2016 ^6^ | Serious | Moderate | Low | Serious | Low | Low | Moderate
Monjardino, 2014 ^8^ | Serious | Low | Low | Serious | Moderate | Low | Moderate
Monjardino, 2015 ^9^ | Serious | Moderate | Low | Serious | Moderate | Low | Moderate
Warensjo-Lemming, 2017 ^7^ | Serious | Low | Moderate | Serious | Moderate | Low | Moderate

ii Dietary Guidelines Advisory Committee. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. US Department of Agriculture, Agricultural Research Service. https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines/advisory-report. Published 2015. Accessed July 9, 2020.

iii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iv Dietary Guidelines Advisory Committee. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. US Department of Agriculture, Agricultural Research Service. https://health.gov/our-work/food-nutrition/2015-2020-dietary-guidelines/advisory-report. Published 2015. Accessed July 9, 2020.

v Abbreviations: BMD, Bone mineral density; BMI, Body mass index; CI, Confidence interval; CVD, Cardiovascular disease; DASH, Dietary Approaches to Stop Hypertension; EPIC, European Investigation into Cancer and Nutrition; EPITeen, Epidemiological Health Investigation of Teenagers in Portugal; f/u, follow-up; KIDMED, Mediterranean Diet Quality Index for children and adolescents; NS, Not significant; OHS, Oslo Health Study; Q, quartile; Ref, Reference; RR, Relative risk; y, year(s)

vi Includes last name of first author, publication year, country, analytic sample size, and select participant characteristics.

vii A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

viii Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )