# List of abbreviations

Abbreviation: Full name
AMDR: Acceptable macronutrient distribution range
BMI: Body mass index
CNPP: Center for Nutrition Policy and Promotion
CVD: Cardiovascular disease
DASH: Dietary Approaches to Stop Hypertension
EVOO: Extra virgin olive oil
FNS: Food and Nutrition Service
f/u: Follow-up
HEI: Healthy Eating Index
HHS: United States Department of Health and Human Services
MUFA: Monounsaturated fatty acids
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
ONGA: Office of Nutrition Guidance and Analysis
%: Percent
PREDIMED: PREvención con DIeta MEDiterránea
PCS: Prospective cohort study design
PUFA: Polyunsaturated fatty acids
RRR: Reduced rank regression
SFA: Saturated fats/fatty acids
SES: Socioeconomic status
USDA: United States Department of Agriculture