# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^xviii^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 8. Dietary Patterns.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders and other factors to be considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on dietary patterns consumed and all-cause mortality. For this systematic review, the target population considered was children through older adults, who are healthy and/or at risk of chronic disease. The interventions or exposures considered were consumption of and/or adherence to a dietary pattern and their comparators were consumption of and/or adherence to a different dietary pattern or different levels of consumption of and/or adherence to a dietary pattern. The outcomes considered were all-cause mortality (i.e., total mortality). The key confounders were sex, age, race/ethnicity, socioeconomic status, alcohol intake (in adults), physical activity, anthropometry, and smoking. The other factors to be considered were energy intake, sodium intake, family history of chronic disease (e.g., diabetes, hypertension, cancer), food allergies, supplemental usage, multiple caregivers, and dentition.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 11 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before and after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Studies that examine consumption of and/or adherence to a | - Studies that
Intervention/exposure | 1 Dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed] including, at a minimum, a description of the foods and beverages in the pattern; ○ Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials | 1a do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary patterns, but do not describe the foods and beverages consumed)
Intervention/exposure | and/or
Intervention/exposure | 2 Diet based on macronutrient distribution outside of the acceptable macronutrient distribution range (AMDR)^xix,xx^; ○ include the macronutrient distribution of carbohydrate, fat, and protein of the diet, and; ○ include at least one macronutrient outside of the AMDR | 2a xamine consumption of and/or adherence to a diet based on macronutrient proportion in which all macronutrients are within the AMDR.; 2b Do not describe the entire macronutrient distribution of the diet (i.e., studies that only examine a single macronutrient in relation to outcomes)
Comparator | - Dietary patterns described by foods and beverages consumed:; ○ Consumption of and/or adherence to a different dietary pattern; ○ Different levels of consumption of and/or adherence to a dietary pattern; - Diets described by macronutrient distribution; ○ Different macronutrient distribution of carbohydrate, fat, and protein | N/A
Outcomes | Studies that report ACM (i.e., total mortality): the total number of deaths from all causes during a specific time-period | Studies that only report cause-specific mortality (total number of deaths from a specific disease, such as cardiovascular disease or cancer)
Date of publication | January 2000 - October 2019 | Articles published prior to January 2000 or after October 2019
Publication status | Articles that have been peer-reviewed | Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, preprints, reports, abstracts, and conference proceedings
Language of publication | Articles published in English | Articles published in languages other than English
Country ^xxi^ | Studies conducted in countries ranked as high or higher human development | Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants; - Males; - Females | - Non-human participants (i.e., animals); - Women during pregnancy and lactation
Age of study participants | - Age at intervention or exposure:; ○ Children and adolescents (ages 2-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older) | - Age at intervention or exposure:; ○ Infants and toddlers (birth to 24 months)
Age of study participants | - Age at outcome:; ○ Children and adolescents (ages 2-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older) | - Age at outcome:; ○ Infants and toddlers (birth to 24 months)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease | - Studies that exclusively enroll participants diagnosed with a disease or hospitalized with illness or injury. (For this criterion, studies that exclusively enroll subjects with obesity will be included.)

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: October 4, 2019
- Date range searched: January 1, 2000-October 4, 2019
- Search Terms:
  - #1 - dietary pattern* OR diet pattern* OR eating pattern* OR food pattern* OR diet quality* OR eating habit* OR dietary habit* OR diet habit* OR food habit* OR beverage habit* OR “Feeding Behavior”[Mesh:NoExp] OR dietary profile* OR food profile* OR diet profile* OR eating profile* OR dietary guideline* OR dietary recommendation* OR dietary intake* OR eating style* OR “Diet, Mediterranean”[Mesh] OR Mediterranean Diet*[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR Dietary Approaches To Stop Hypertension Diet* OR DASH diet* OR “Diet, Gluten-Free”[Mesh] OR Gluten Free diet* OR prudent diet* OR “Diet, Paleolithic”[Mesh] OR Paleolithic Diet* OR “Diet, Vegetarian”[Mesh] OR vegetarian diet*[tiab] OR vegan diet* OR “Diet, Healthy”[Mesh] OR plant based diet* OR “Diet, Western”[Mesh] OR western diet* OR “Diet, Carbohydrate-Restricted”[Mesh] OR low-carbohydrate diet* OR high carbohydrate diet* OR Ketogenic Diet* OR Nordic Diet* OR “Diet, Fat-Restricted”[Mesh] OR “Diet, High-Fat”[Mesh] OR “Diet, High-Protein”[Mesh] OR high protein diet*[tiab] OR protein intake* OR high-fat diet* OR low fat diet* OR “Diet, Protein-Restricted”[Mesh] OR low protein diet* OR “Diet, Sodium-Restricted”[Mesh] OR low-sodium diet* OR low salt diet* OR ((“Dietary Proteins”[Mesh] OR dietary protein*[tiab] OR “Dietary Carbohydrates”[Mesh] OR dietary carbohydrate*[tiab] OR “Dietary Fats”[Mesh] OR dietary fat*[tiab] OR hypocaloric OR hypo-caloric) AND (diet[tiab] OR diets[tiab] OR consumption[tiab] OR intake[tiab] OR supplement*[tiab])) OR ((“Guideline Adherence”[Mesh] OR guideline adherence*)AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage*[tiab] OR nutrition*[tiab])) OR diet score* OR diet quality score* OR diet quality index* OR kidmed OR diet index* OR dietary index* OR food score* OR MedDietScore OR healthy eating index[tiab] OR ((pattern[tiab] OR patterns[tiab] OR consumption[tiab] OR habit*[tiab]) AND (“Diet”[Mesh:NoExp] OR diet[tiab] OR diets[tiab] OR dietary[tiab] OR “Food”[Mesh] OR food[tiab] OR foods[tiab] OR “Beverages”[Mesh] OR beverage[tiab] OR beverages[tiab]))
  - #2 - "Mortality”[Mesh] OR “mortality” [Subheading] OR mortality [tiab]
  - #3 - (#1 AND #2)
  - #4 - (#1 AND #2) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2000/01/01 to 2019/10/04; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) searched: October 4, 2019
- Date range searched: January 1, 2000-October 4, 2019
- Search Terms:
  - #1 - “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality*” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR “beverage habit*” OR [mh ^“Feeding Behavior”] OR “feeding behavior*” OR “dietary profile*” OR “food profile*” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR [mh “Diet, Mediterranean”] OR “Mediterranean Diet*” OR [mh “Dietary Approaches To Stop Hypertension”] OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR [mh “Diet, Gluten-Free”] OR “Gluten Free diet*” OR “prudent diet*” OR [mh “Diet, Paleolithic”] OR “Paleolithic Diet*” OR [mh “Diet, Vegetarian”] OR “vegetarian diet*” OR “vegan diet*” OR [mh “Diet, Healthy”] OR “healthy diet” OR “plant based diet*” OR [mh “Diet, Western”] OR “western diet*” OR [mh “Diet, Carbohydrate-Restricted”] OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, High-Protein”] OR “high protein diet*” OR “protein intake*” OR “high-fat diet*” OR “low fat diet*” OR [mh “Diet, Protein-Restricted”] OR “low protein diet*” OR [mh “Diet, Sodium-Restricted”] OR “low-sodium diet*” OR “low salt diet*”
  - #2 - (([mh “Dietary Proteins”] OR “dietary protein*” OR [mh “Dietary Carbohydrates”] OR “dietary carbohydrate*” OR [mh “Dietary Fats”] OR “dietary fat*” OR hypocaloric OR hypo-caloric) NEAR/6 (diet OR diets OR consumption OR intake OR supplement*))
  - #3 - (([mh “Guideline Adherence”] OR guideline adherence*) NEAR/6 (diet OR dietary OR food OR beverage* OR nutrition*))
  - #4 - (“diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index*”):ti,ab,kw
  - #5 - ((pattern OR patterns OR consumption OR habit*) NEAR/6 ([mh ^“Diet”] OR diet OR diets OR dietary OR [mh “Food”] OR food OR foods OR [mh “Beverages”] OR beverage OR beverages))
  - #6 - #1 OR #2 OR #3 OR #4 OR #5
  - #7 - [mh Mortality] OR [mh /MO]
  - #8 - (mortality):ti,ab,kw
  - #9 - #7 OR #8
  - #10 - #6 AND #9” with Publication Year from 2000 to 2019, in Trials (Word variations have been searched)

#### Embase

- Provider: Elsevier
- Date(s) searched: October 4, 2019
- Date range searched: January 1, 2000-October 4, 2019
- Search Terms:
  - #1 - ‘feeding behavior’/de OR ‘mediterranean diet’/exp OR ‘dash diet’/exp OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/exp OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein diet’/exp OR ‘protein restriction’/exp OR ‘sodium restriction’/exp
  - #2 - ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality*’:ab,ti OR ‘eating habit*’:ab,ti OR ‘dietary habit*’:ab,ti OR ‘diet habit*’:ab,ti OR ‘food habit*’:ab,ti OR ‘beverage habit*’:ab,ti OR ‘feeding behavior*’:ab,ti OR ‘dietary profile*’:ab,ti OR ‘food profile*’:ab,ti OR ‘diet profile*’:ab,ti OR ‘eating profile*’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake*’:ab,ti OR ‘eating style*’:ab,ti OR ‘mediterranean diet*’:ab,ti OR ‘dietary approaches to stop hypertension diet*’:ab,ti OR ‘dash diet*’:ab,ti OR ‘gluten free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘paleolithic diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘healthy diet’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘low-carbohydrate diet*’:ab,ti OR ‘high carbohydrate diet*’:ab,ti OR ‘ketogenic diet*’:ab,ti OR ‘nordic diet*’:ab,ti OR ‘high protein diet*’:ab,ti OR ‘protein intake*’:ab,ti OR ‘high-fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low protein diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti
  - #3 - ((‘dietary protein*’ OR ‘dietary carbohydrate*’ OR ‘dietary fat*’ OR hypocaloric OR ‘hypo caloric’) NEAR/6 (diet OR diets OR consumption OR intake OR supplement*)):ab,ti
  - #4 - (‘guideline adherence*’ NEAR/6 (diet OR dietary OR food OR beverage* OR nutrition*)):ab,ti
  - #5 - ‘diet score*’:ab,ti OR ‘diet quality score*’:ab,ti OR ‘diet quality index*’:ab,ti OR kidmed:ab,ti OR ‘diet index*’:ab,ti OR ‘dietary index*’:ab,ti OR ‘food score*’:ab,ti OR meddietscore:ab,ti OR ‘healthy eating index*’:ab,ti
  - #6 - ((pattern OR patterns OR consumption OR habit*) NEAR/6 (diet OR diets OR dietary OR food OR foods OR beverage OR beverages)):ab,ti
  - #7 - #1 OR #2 OR #3 OR #4 OR #5 OR #6
  - #8 - ‘mortality’/exp
  - #9 - mortality:ab,ti
  - #10 - #8 OR #9
  - #11 - #7 AND #10
  - #12 - #7 AND #10 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2019]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining this systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 10 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between dietary patterns and all-cause mortality. The literature search yielded 14742 raw results of articles. During title screening, 9853 articles were screened out. During abstract screening, 1141 articles were screened out. During full-text screening, 400 articles were screened out. During the hand search, 0 additional articles were identified to include. A total of 153 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles

The table below lists the articles excluded after full-text screening for this systematic review question. At least one reason for exclusion is provided for each article, which may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table 12 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1 | [Unavailable]. Correction: The impact of dietary habits and metabolic risk factors on cardiovascular and diabetes mortality in countries of the Middle East and North Africa in 2010: a comparative risk assessment analysis. BMJ Open. 2019. 9:e006385corr1 https://www.ncbi.nlm.nih.gov/pubmed/31048450 | Study design, Publication Status
2 | [Unavailable]. Dietary alpha-Linolenic Acid, Marine omega-3 Fatty Acids, and Mortality in a Population With High Fish Consumption: Findings From the PREvencion con DIeta MEDiterranea (PREDIMED) Study. J Am Heart Assoc. 2016. 5:#pages# https://www.ncbi.nlm.nih.gov/pubmed/26873691 | Study Design, Intervention/Exposure, Publication Status
3 | [Unavailable]. Erratum for Juanola-Falgarona et al. Dietary intake of vitamin K is inversely associated with mortality risk. J Nutr 2014;144:743-50. J Nutr. 2016. 146:653 https://www.ncbi.nlm.nih.gov/pubmed/26933059 26933059 | Study Design, Intervention/Exposure, Publication Status
4 | [Unavailable]. Vegetarian diets aid longevity, reduce risk of ACM. But results are more significant in men than women. Further research is needed to determine why. Duke Med Health News. 2013. 19:4–5 https://www.ncbi.nlm.nih.gov/pubmed/23984452 | Study design, Publication Status
5 | Abrahams, Z, McHiza, Z, Steyn, NP. Diet and mortality rates in Sub-Saharan Africa: stages in the nutrition transition. BMC Public Health. 2011. 11:801 https://www.ncbi.nlm.nih.gov/pubmed/21995618 21995618 | Intervention/Exposure, Outcome
6 | Abu-Saad, K, Novikov, I, Gimpelevitz, I, Benderly, M, Alpert, G, Goldbourt, U, Kalter-Leibovici, O. Micronutrient intake and adherence to DASH diet are associated with incident major adverse cardiovascular events and ACM in a bi-ethnic population. European heart journal. 2017. 38:1120- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01468739/full | Study design, Publication Status
7 | Afshin, A, Micha, R, Khatibzadeh, S, Fahimi, S, Shi, P, Powles, J, Singh, G, Yakoob, MY, Abdollahi, M, Al-Hooti, S, Farzadfar, F, Houshiar-Rad, A, Hwalla, N, Koksal, E, Musaiger, A, Pekcan, G, Sibai, AM, Zaghloul, S, Danaei, G, Ezzati, M, Mozaffarian, D. The impact of dietary habits and metabolic risk factors on cardiovascular and diabetes mortality in countries of the Middle East and North Africa in 2010: a comparative risk assessment analysis. BMJ Open. 2015. 5:e006385 https://www.ncbi.nlm.nih.gov/pubmed/25995236 | Outcome, Country
8 | Agarwal, E, Ferguson, M, Banks, M, Vivanti, A, Batterham, M, Bauer, J, Capra, S, Isenring, E. Malnutrition, poor food intake, and adverse healthcare outcomes in non-critically ill obese acute care hospital patients. Clin Nutr. 2019. 38:759–766 https://www.ncbi.nlm.nih.gov/pubmed/29559233 29559233 | Intervention/Exposure, Health Status
9 | Ahmed, HM, Blaha, MJ, Nasir, K, Jones, SR, Rivera, JJ, Agatston, A, Blankstein, R, Wong, ND, Lakoski, S, Budoff, MJ, Burke, GL, Sibley, CT, Ouyang, P, Blumenthal, RS. Low-risk lifestyle, coronary calcium, cardiovascular events, and mortality: results from MESA. Am J Epidemiol. 2013. 178:12–21 https://www.ncbi.nlm.nih.gov/pubmed/23733562 23733562 | Intervention/Exposure
10 | Aigner, A, Becher, H, Jacobs, S, Wilkens, LR, Boushey, CJ, Le Marchand, L, Haiman, CA, Maskarinec, G. Low diet quality and the risk of stroke mortality: the multiethnic cohort study. Eur J Clin Nutr. 2018. 72:1035–1045 https://www.ncbi.nlm.nih.gov/pubmed/29426930 29426930 | Outcome
11 | Akbaraly, T, Sabia, S, Hagger-Johnson, G, Tabak, AG, Shipley, MJ, Jokela, M, Brunner, EJ, Hamer, M, Batty, GD, Singh-Manoux, A, Kivimaki, M. Does overall diet in midlife predict future aging phenotypes? A cohort study. Am J Med. 2013. 126:411–419.e3 https://www.ncbi.nlm.nih.gov/pubmed/23582933 23582933 | Outcome
12 | Akinyemiju, T, Moore, JX, Pisu, M, Lakoski, SG, Shikany, J, Goodman, M, Judd, SE. A prospective study of dietary patterns and cancer mortality among Blacks and Whites in the REGARDS cohort. Int J Cancer. 2016. 139:2221–31 https://www.ncbi.nlm.nih.gov/pubmed/27459634 27459634 | Outcome
13 | Alberti, A, Fruttini, D, Fidanza, F. The Mediterranean Adequacy Index: further confirming results of validity. Nutr Metab Cardiovasc Dis. 2009. 19:61–6 https://www.ncbi.nlm.nih.gov/pubmed/18337072 18337072 | Study Design, Outcome
14 | Allan, GM, Ivers, N, Sharma, AM. Diets for weight loss and prevention of negative health outcomes. Can Fam Physician. 2011. 57:894–5 https://www.ncbi.nlm.nih.gov/pubmed/21841109 21841109 | Study Design
15 | Alshahrani, SM, Fraser, GE, Sabate, J, Knutsen, R, Shavlik, D, Mashchak, A, Lloren, JI, Orlich, MJ. Red and Processed Meat and Mortality in a Low Meat Intake Population. Nutrients. 2019. 11:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30875776 | Intervention/Exposure
16 | Alvarez-Alvarez, I, Zazpe, I, Perez de Rojas, J, Bes-Rastrollo, M, Ruiz-Canela, M, Fernandez-Montero, A, Hidalgo-Santamaria, M, Martinez-Gonzalez, MA. Mediterranean diet, physical activity and their combined effect on ACM: The Seguimiento Universidad de Navarra (SUN) cohort. Prev Med. 2018. 106:45–52 https://www.ncbi.nlm.nih.gov/pubmed/28964855 28964855 | Intervention/Exposure
17 | Amrock, SM, Weitzman, M. Multiple biomarkers for mortality prediction in peripheral arterial disease. Vasc Med. 2016. 21:105–12 https://www.ncbi.nlm.nih.gov/pubmed/26762418 26762418 | Study Design, Intervention/Exposure
18 | Appleby, PN, Crowe, FL, Bradbury, KE, Travis, RC, Key, TJ. Mortality in vegetarians and comparable nonvegetarians in the United Kingdom. Am J Clin Nutr. 2016. 103:218–30 https://www.ncbi.nlm.nih.gov/pubmed/26657045 26657045 | Intervention/Exposure
19 | Appleby, PN, Key, TJ, Thorogood, M, Burr, ML, Mann, J. Mortality in British vegetarians. Public Health Nutr. 2002. 5:29–36 https://www.ncbi.nlm.nih.gov/pubmed/12001975 12001975 | Intervention/Exposure
20 | Argos, M, Melkonian, S, Parvez, F, Rakibuz-Zaman, M, Ahmed, A, Chen, Y, Ahsan, H. A population-based prospective study of energy-providing nutrients in relation to all-cause cancer mortality and cancers of digestive organs mortality. Int J Cancer. 2013. 133:2422–8 https://www.ncbi.nlm.nih.gov/pubmed/23650102 23650102 | Country
21 | Argyridou, S, Zaccardi, F, Davies, MJ, Khunti, K, Yates, T. Relevance of physical function in the association of red and processed meat intake with all-cause, cardiovascular, and cancer mortality. Nutr Metab Cardiovasc Dis. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31377183 | Intervention/Exposure
22 | Asadi, Z, Shafiee, M, Sadabadi, F, Heidari-Bakavoli, A, Moohebati, M, Khorrami, MS, Darroudi, S, Heidari, S, Hoori, T, Tayefi, M, Mohammadi, F, Esmaeily, H, Safarian, M, Ghayour-Mobarhan, M, Ferns, GA. Association of dietary patterns and risk of cardiovascular disease events in the MASHAD cohort study. J Hum Nutr Diet. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31332855 | Outcome
23 | Awuor, L, Melles, S. The influence of environmental and health indicators on premature mortality: An empirical analysis of the City of Toronto’s 140 neighborhoods. Health Place. 2019. 58:102155 https://www.ncbi.nlm.nih.gov/pubmed/31252289 31252289 | Intervention/Exposure
24 | Baer, HJ, Glynn, RJ, Hu, FB, Hankinson, SE, Willett, WC, Colditz, GA, Stampfer, M, Rosner, B. Risk factors for mortality in the nurses’ health study: a competing risks analysis. Am J Epidemiol. 2011. 173:319–29 https://www.ncbi.nlm.nih.gov/pubmed/21135028 21135028 | Intervention/Exposure
25 | Banegas, JR, LeÃ³n-MuÃ±oz, LM, Guallar-CastillÃ³n, P, Graciani, A, RodrÃ-guez-Artalejo, F. Self-reported adherence to nonpharmacological treatment and association with mortality over 6 years: Population-based study in older persons with hypercholesterolemia. Journal of the American Geriatrics Society. 2009. 57:2287–2292 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L355759201. 10.1111/j.1532-5415.2009.02556.x 19874407 | Intervention/Exposure
26 | Barrington, WE, White, E. Mortality outcomes associated with intake of fast-food items and sugar-sweetened drinks among older adults in the Vitamins and Lifestyle (VITAL) study. Public Health Nutr. 2016. 19:3319–3326 https://www.ncbi.nlm.nih.gov/pubmed/27338763 27338763 | Intervention/Exposure
27 | Bates, CJ, Hamer, M, Mishra, GD. A study of relationships between bone-related vitamins and minerals, related risk markers, and subsequent mortality in older British people: the National Diet and Nutrition Survey of People Aged 65 Years and Over. Osteoporos Int. 2012. 23:457–66 https://www.ncbi.nlm.nih.gov/pubmed/21380638 21380638 | Intervention/Exposure
28 | Bathrellou, E, Kontogianni, MD, Chrysanthopoulou, E, Georgousopoulou, E, Chrysohoou, C, Pitsavos, C, Panagiotakos, D. Adherence to a DASH-style diet and cardiovascular disease risk: The 10-year follow-up of the ATTICA study. Nutr Health. 2019. 25:225–230 https://www.ncbi.nlm.nih.gov/pubmed/31319758 31319758 | Outcome
29 | Beddhu, S, Chen, X, Wei, G, Raj, D, Raphael, KL, Boucher, R, Chonchol, MB, Murtaugh, MA, Greene, T. Associations of Protein-Energy Wasting Syndrome Criteria With Body Composition and Mortality in the General and Moderate Chronic Kidney Disease Populations in the United States. Kidney Int Rep. 2017. 2:390–399 https://www.ncbi.nlm.nih.gov/pubmed/28840197 28840197 | Intervention/Exposure
30 | Belanger, M, Poirier, M, Jbilou, J, Scarborough, P. Modelling the impact of compliance with dietary recommendations on cancer and cardiovascular disease mortality in Canada. Public Health. 2014. 128:222–30 https://www.ncbi.nlm.nih.gov/pubmed/24612957 24612957 | Study Design, Intervention/Exposure, Outcome
31 | Bell, GA, Kantor, ED, Lampe, JW, Kristal, AR, Heckbert, SR, White, E. Intake of long-chain omega-3 fatty acids from diet and supplements in relation to mortality. Am J Epidemiol. 2014. 179:710–20 https://www.ncbi.nlm.nih.gov/pubmed/24496442 24496442 | Intervention/Exposure
32 | Bellavia, A, Stilling, F, Wolk, A. High red meat intake and all-cause cardiovascular and cancer mortality: is the risk modified by fruit and vegetable intake?. Am J Clin Nutr. 2016. 104:1137–1143 https://www.ncbi.nlm.nih.gov/pubmed/27557655 27557655 | Intervention/Exposure
33 | Berard, E, Bongard, V, Haas, B, Dallongeville, J, Moitry, M, Cottel, D, Ruidavets, JB, Ferrieres, J. Score of adherence to 2016 European cardiovascular prevention guidelines is an independent determinant of cardiovascular and ACM in a French general population. European heart journal. 2017. 38:1064- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01468665/full | Study Design, Intervention/Exposure, Publication Status
34 | Berard, E, Bongard, V, Haas, B, Dallongeville, J, Moitry, M, Cottel, D, Ruidavets, JB, Ferrieres, J. Score of Adherence to 2016 European Cardiovascular Prevention Guidelines Predicts Cardiovascular and ACM in the General Population. Can J Cardiol. 2017. 33:1298–1304 https://www.ncbi.nlm.nih.gov/pubmed/28866076 28866076 | Intervention/Exposure
35 | Beydoun, MA, Beydoun, HA, Mode, N, Dore, GA, Canas, JA, Eid, SM, Zonderman, AB. Racial disparities in adult all-cause and cause-specific mortality among us adults: mediating and moderating factors. BMC Public Health. 2016. 16:1113 https://www.ncbi.nlm.nih.gov/pubmed/27770781 27770781 | Intervention/Exposure
36 | Beydoun, HA, Huang, S, Beydoun, MA, Hossain, S, Zonderman, AB. Mediating-Moderating Effect of Allostatic Load on the Association between Dietary Approaches to Stop Hypertension Diet and All-Cause and Cause-Specific Mortality: 2001-2010 National Health and Nutrition Examination Surveys. Nutrients. 2019. 11:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31569527 | Intervention/Exposure
37 | Biesbroek, S, Bueno-de-Mesquita, HB, Peeters, PH, Verschuren, WM, van der Schouw, YT, Kramer, GF, Tyszler, M, Temme, EH. Reducing our environmental footprint and improving our health: greenhouse gas emission and land use of usual diet and mortality in EPIC-NL: a prospective cohort study. Environ Health. 2014. 13:27 https://www.ncbi.nlm.nih.gov/pubmed/24708803 24708803 | Intervention/Exposure
38 | Bihan, H, Backholer, K, Peeters, A, Stevenson, CE, Shaw, JE, Magliano, DJ. Socioeconomic Position and Premature Mortality in the AusDiab Cohort of Australian Adults. Am J Public Health. 2016. 106:470–7 https://www.ncbi.nlm.nih.gov/pubmed/26794164 26794164 | Intervention/Exposure
39 | Bjorck, L, Rosengren, A, Winkvist, A, Capewell, S, Adiels, M, Bandosz, P, Critchley, J, Boman, K, Guzman-Castillo, M, O’Flaherty, M, Johansson, I. Changes in Dietary Fat Intake and Projections for Coronary Heart Disease Mortality in Sweden: A Simulation Study. PLoS One. 2016. 11:e0160474 https://www.ncbi.nlm.nih.gov/pubmed/27490257 27490257 | Study Design, Intervention/Exposure, Outcome
40 | Bjorkman, MP, Suominen, MH, Pitkala, KH, Finne-Soveri, HU, Tilvis, RS. Porvoo sarcopenia and nutrition trial: effects of protein supplementation on functional performance in home-dwelling sarcopenic older people - study protocol for a randomized controlled trial. Trials. 2013. 14:387 https://www.ncbi.nlm.nih.gov/pubmed/24225081 24225081 | Study Design
41 | Blekkenhorst, LC, Lewis, JR, Bondonno, CP, Sim, M, Devine, A, Zhu, K, Lim, WH, Woodman, RJ, Beilin, LJ, Thompson, PL, Prince, RL, Hodgson, JM. Vegetable diversity in relation with subclinical atherosclerosis and 15-year atherosclerotic vascular disease deaths in older adult women. Eur J Nutr. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30656478 | Intervention/Exposure, Outcome
42 | Bonaccio, M, Di Castelnuovo, A, Bonanni, A, Costanzo, S, De Lucia, F, Pounis, G, Zito, F, Donati, MB, de Gaetano, G, Iacoviello, L. Adherence to a Mediterranean diet is associated with a better health-related quality of life: a possible role of high dietary antioxidant content. BMJ Open. 2013. 3:#pages# https://www.ncbi.nlm.nih.gov/pubmed/23943771 | Study Design, Outcome
43 | Bonaccio, M, Di Castelnuovo, A, Costanzo, S, De Curtis, A, Persichillo, M, Cerletti, C, Donati, MB, de Gaetano, G, Iacoviello, L. Impact of combined healthy lifestyle factors on survival in an adult general population and in high-risk groups: prospective results from the Moli-sani Study. J Intern Med. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30993789 | Intervention/Exposure
44 | Bonaccio, M, Di Castelnuovo, A, Costanzo, S, Persichillo, M, De Curtis, A, Cerletti, C, Donati, MB, de Gaetano, G, Iacoviello, L. Interaction between Mediterranean diet and statins on mortality risk in patients with cardiovascular disease: Findings from the Moli-sani Study. Int J Cardiol. 2019. 276:248–254 https://www.ncbi.nlm.nih.gov/pubmed/30527993 30527993 | Health Status
45 | Bonaccio, M, Di Castelnuovo, A, Costanzo, S, Persichillo, M, De Curtis, A, Donati, MB, de Gaetano, G, Iacoviello, L. Adherence to the traditional Mediterranean diet and mortality in subjects with diabetes. Prospective results from the MOLI-SANI study. Eur J Prev Cardiol. 2016. 23:400–7 https://www.ncbi.nlm.nih.gov/pubmed/25648935 25648935 | Health Status
46 | Bonaccio, M, Di Castelnuovo, A, De Curtis, A, Costanzo, S, Bracone, F, Persichillo, M, Donati, MB, de Gaetano, G, Iacoviello, L. Nut consumption is inversely associated with both cancer and total mortality in a Mediterranean population: prospective results from the Moli-sani study. Br J Nutr. 2015. 114:804–11 https://www.ncbi.nlm.nih.gov/pubmed/26313936 26313936 | Intervention/Exposure
47 | Bondonno, NP, Dalgaard, F, Kyro, C, Murray, K, Bondonno, CP, Lewis, JR, Croft, KD, Gislason, G, Scalbert, A, Cassidy, A, Tjonneland, A, Overvad, K, Hodgson, JM. Flavonoid intake is associated with lower mortality in the Danish Diet Cancer and Health Cohort. Nat Commun. 2019. 10:3651 https://www.ncbi.nlm.nih.gov/pubmed/31409784 31409784 | Intervention/Exposure
48 | Boniface, DR, Tefft, ME. Dietary fats and 16-year coronary heart disease mortality in a cohort of men and women in Great Britain. Eur J Clin Nutr. 2002. 56:786–92 https://www.ncbi.nlm.nih.gov/pubmed/12122556 12122556 | Intervention/Exposure
49 | Broeska, VE, Lengyel, CO, Tate, RB. Nutritional risk and 5-year mortality of older community-dwelling Canadian men: the Manitoba Follow-Up Study. J Nutr Gerontol Geriatr. 2013. 32:317–29 https://www.ncbi.nlm.nih.gov/pubmed/24224939 24224939 | Study Design, Intervention/Exposure
50 | Brown, JC, Harhay, MO, Harhay, MN. Physical activity, diet quality, and mortality among sarcopenic older adults. Aging Clin Exp Res. 2017. 29:257–263 https://www.ncbi.nlm.nih.gov/pubmed/27020695 27020695 | Health Status
51 | Brunner, E. More evidence that a healthy lifestyle matters: Converting epidemiology to policy. Evidence-Based Healthcare and Public Health. 2005. 9:108–110 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L40568191, 10.1016/j.ehbc.2005.01.037 | Study Design
52 | Budhathoki, S, Sawada, N, Iwasaki, M, Yamaji, T, Goto, A, Kotemori, A, Ishihara, J, Takachi, R, Charvat, H, Mizoue, T, Iso, H, Tsugane, S. Association of Animal and Plant Protein Intake With All-Cause and Cause-Specific Mortality. JAMA Intern Med. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31449285 | Intervention/Exposure
53 | Bui, Q. Dietary fat modification and the risk of future cardiovascular events and mortality. Am Fam Physician. 2013. 87:609–10 https://www.ncbi.nlm.nih.gov/pubmed/23668523 23668523 | Study Design
54 | Buil-Cosiales, P, Zazpe, I, Toledo, E, Corella, D, Salas-Salvado, J, Diez-Espino, J, Ros, E, Fernandez-Creuet Navajas, J, Santos-Lozano, JM, Aros, F, Fiol, M, Castaner, O, Serra-Majem, L, Pinto, X, Lamuela-Raventos, RM, Marti, A, Basterra-Gortari, FJ, Sorli, JV, Verdu-Rotellar, JM, Basora, J, Ruiz-Gutierrez, V, Estruch, R, Martinez-Gonzalez, MA. Fiber intake and ACM in the Prevencion con Dieta Mediterranea (PREDIMED) study. Am J Clin Nutr. 2014. 100:1498–507 https://www.ncbi.nlm.nih.gov/pubmed/25411285 25411285 | Intervention/Exposure
55 | Burger, KN, Beulens, JW, Boer, JM, Spijkerman, AM, van der, Dl A. Dietary glycemic load and glycemic index and risk of coronary heart disease and stroke in Dutch men and women: the EPIC-MORGEN study. PLoS One. 2011. 6:e25955 https://www.ncbi.nlm.nih.gov/pubmed/21998729 21998729 | Outcome
56 | Burger, KN, Beulens, JW, van der Schouw, YT, Sluijs, I, Spijkerman, AM, Sluik, D, Boeing, H, Kaaks, R, Teucher, B, Dethlefsen, C, Overvad, K, Tjonneland, A, Kyro, C, Barricarte, A, Bendinelli, B, Krogh, V, Tumino, R, Sacerdote, C, Mattiello, A, Nilsson, PM, Orho-Melander, M, Rolandsson, O, Huerta, JM, Crowe, F, Allen, N, Nothlings, U. Dietary fiber, carbohydrate quality and quantity, and mortality risk of individuals with diabetes mellitus. PLoS One. 2012. 7:e43127 https://www.ncbi.nlm.nih.gov/pubmed/22927948 22927948 | Health Status
57 | Burke, V, Zhao, Y, Lee, AH, Hunter, E, Spargo, RM, Gracey, M, Smith, RM, Beilin, LJ, Puddey, IB. Health-related behaviours as predictors of mortality and morbidity in Australian Aborigines. Prev Med. 2007. 44:135–42 https://www.ncbi.nlm.nih.gov/pubmed/17069878 17069878 | Intervention/Exposure
58 | Buyken, AE, Flood, V, Empson, M, Rochtchina, E, Barclay, AW, Brand-Miller, J, Mitchell, P. Carbohydrate nutrition and inflammatory disease mortality in older adults. Am J Clin Nutr. 2010. 92:634–43 https://www.ncbi.nlm.nih.gov/pubmed/20573797 20573797 | Intervention/Exposure, Outcome
59 | Cai, H, Shu, XO, Gao, YT, Li, H, Yang, G, Zheng, W. A prospective study of dietary patterns and mortality in Chinese women. Epidemiology. 2007. 18:393–401 https://www.ncbi.nlm.nih.gov/pubmed/17435450 17435450 | Country
60 | Campmans-Kuijpers, MJ, Sluijs, I, Nothlings, U, Freisling, H, Overvad, K, Boeing, H, Masala, G, Panico, S, Tumino, R, Sieri, S, Johansson, I, Winkvist, A, Katzke, VA, Kuehn, T, Nilsson, PM, Halkjaer, J, Tjonneland, A, Spijkerman, AM, Arriola, L, Sacerdote, C, Barricarte, A, May, AM, Beulens, JW. The association of substituting carbohydrates with total fat and different types of fatty acids with mortality and weight change among diabetes patients. Clin Nutr. 2016. 35:1096–102 https://www.ncbi.nlm.nih.gov/pubmed/26342536 26342536 | Health Status
61 | Campmans-Kuijpers, MJ, Sluijs, I, Nothlings, U, Freisling, H, Overvad, K, Weiderpass, E, Fagherazzi, G, Kuhn, T, Katzke, VA, Mattiello, A, Sonestedt, E, Masala, G, Agnoli, C, Tumino, R, Spijkerman, AM, Barricarte, A, Ricceri, F, Chamosa, S, Johansson, I, Winkvist, A, Tjonneland, A, Sluik, D, Boeing, H, Beulens, JW. Isocaloric substitution of carbohydrates with protein: the association with weight change and mortality among patients with type 2 diabetes. Cardiovasc Diabetol. 2015. 14:39 https://www.ncbi.nlm.nih.gov/pubmed/25896172 25896172 | Health Status
62 | Capewell, S, O’Flaherty, M. Can dietary changes rapidly decrease cardiovascular mortality rates?. Eur Heart J. 2011. 32:1187–9 https://www.ncbi.nlm.nih.gov/pubmed/21367835 21367835 | Study design
63 | Capewell, S, O’Flaherty, M. Rapid mortality falls after risk-factor changes in populations. Lancet. 2011. 378:752–3 https://www.ncbi.nlm.nih.gov/pubmed/21414659 21414659 | Study Design
64 | Casas, R, Sacanella, E, Urpi-Sarda, M, Chiva-Blanch, G, Ros, E, Martinez-Gonzalez, MA, Covas, MI, Salas-Salvado, J, Fiol, M, Aros, F, Estruch, R. The effects of the mediterranean diet on biomarkers of vascular wall inflammation and plaque vulnerability in subjects with high risk for cardiovascular disease. A randomized trial. PLoS One. 2014. 9:e100084 https://www.ncbi.nlm.nih.gov/pubmed/24925270 24925270 | Outcome
65 | Castro-Quezada, I, Sanchez-Villegas, A, Estruch, R, Salas-Salvado, J, Corella, D, Schroder, H, Alvarez-Perez, J, Ruiz-Lopez, MD, Artacho, R, Ros, E, Bullo, M, Covas, MI, Ruiz-Gutierrez, V, Ruiz-Canela, M, Buil-Cosiales, P, Gomez-Gracia, E, Lapetra, J, Pinto, X, Aros, F, Fiol, M, Lamuela-Raventos, RM, Martinez-Gonzalez, MA, Serra-Majem, L. A high dietary glycemic index increases total mortality in a Mediterranean population at high cardiovascular risk. PLoS One. 2014. 9:e107968 https://www.ncbi.nlm.nih.gov/pubmed/25250626 25250626 | Intervention/Exposure
66 | Cerhan, JR, Potter, JD, Gilmore, JM, Janney, CA, Kushi, LH, Lazovich, D, Anderson, KE, Sellers, TA, Folsom, AR. Adherence to the AICR cancer prevention recommendations and subsequent morbidity and mortality in the Iowa Women’s Health Study cohort. Cancer Epidemiol Biomarkers Prev. 2004. 13:1114–20 https://www.ncbi.nlm.nih.gov/pubmed/15247121 15247121 | Intervention/Exposure
67 | Chang, AR, Lazo, M, Appel, LJ, GutiÃ©rrez, OM, Grams, ME. High dietary phosphorus intake is associated with ACM: Results from NHANES III1-3. American Journal of Clinical Nutrition. 2014. 99:320–327 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L372244325. 10.3945/ajcn.113.073148 | Intervention/Exposure
68 | Chang, WC, Wahlqvist, ML, Chang, HY, Hsu, CC, Lee, MS, Wang, WS, Hsiung, CA. A bean-free diet increases the risk of ACM among Taiwanese women: the role of the metabolic syndrome. Public Health Nutr. 2012. 15:663–72 https://www.ncbi.nlm.nih.gov/pubmed/21899787 21899787 | Intervention/Exposure
69 | Chen, X, Wei, G, Jalili, T, Metos, J, Giri, A, Cho, ME, Boucher, R, Greene, T, Beddhu, S. The Associations of Plant Protein Intake With ACM in CKD. Am J Kidney Dis. 2016. 67:423–30 https://www.ncbi.nlm.nih.gov/pubmed/26687923 26687923 | Intervention/Exposure, Health Status
70 | Chen, Y, McClintock, TR, Segers, S, Parvez, F, Islam, T, Ahmed, A, Rakibuz-Zaman, M, Hasan, R, Sarwar, G, Ahsan, H. Prospective investigation of major dietary patterns and risk of cardiovascular mortality in Bangladesh. Int J Cardiol. 2013. 167:1495–501 https://www.ncbi.nlm.nih.gov/pubmed/22560940 22560940 | Country
71 | Chiuve, SE, Sampson, L, Willett, WC. The association between a nutritional quality index and risk of chronic disease. Am J Prev Med. 2011. 40:505–13 https://www.ncbi.nlm.nih.gov/pubmed/21496749 21496749 | Intervention/Exposure
72 | Chlebowski, RT, Anderson, GL, Manson, JE, Prentice, RL, Aragaki, AK, Snetselaar, L, Beresford, SAA, Kuller, LH, Johnson, K, Lane, D, Luo, J, Rohan, TE, Jiao, L, Barac, A, Womack, C, Coday, M, Datta, M, Thomson, CA. Low-Fat Dietary Pattern and Cancer Mortality in the Women’s Health Initiative (WHI) Randomized Controlled Trial. JNCI Cancer Spectr. 2018. 2:pky065 https://www.ncbi.nlm.nih.gov/pubmed/31360880 31360880 | Outcome
73 | Chlebowski, RT, Aragaki, AK, Anderson, GL, Thomson, CA, Manson, JE, Simon, MS, Howard, BV, Rohan, TE, Snetselaar, L, Lane, D, ,. Low-fat dietary pattern and breast cancer mortality in the Women’s Health Initiative (WHI) randomized trial. Cancer research. 2016. 76:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01294296/full | Study design, Publication Status
74 | Chlebowski, RT, Aragaki, AK, Anderson, GL, Thomson, CA, Manson, JE, Simon, MS, Howard, BV, Rohan, TE, Snetselar, L, Lane, D, Barrington, W, Vitolins, MZ, Womack, C, Qi, L, Hou, L, Thomas, F, Prentice, RL. Low-Fat Dietary Pattern and Breast Cancer Mortality in the Women’s Health Initiative Randomized Controlled Trial. J Clin Oncol. 2017. 35:2919–2926 https://www.ncbi.nlm.nih.gov/pubmed/28654363 28654363 | Outcome
75 | Cicero, AF, Benelli, M, Brancaleoni, M, Dainelli, G, Merlini, D, Negri, R. Middle and Long-Term Impact of a Very Low-Carbohydrate Ketogenic Diet on Cardiometabolic Factors: A Multi-Center, Cross-Sectional, Clinical Study. High Blood Press Cardiovasc Prev. 2015. 22:389–94 https://www.ncbi.nlm.nih.gov/pubmed/25986079 25986079 | Outcome
76 | Cobiac, LJ, Scarborough, P. Modelling the health co-benefits of sustainable diets in the UK, France, Finland, Italy and Sweden. Eur J Clin Nutr. 2019. 73:624–633 https://www.ncbi.nlm.nih.gov/pubmed/30755710 30755710 | Study Design, Intervention/Exposure
77 | Cohen, HW, Hailpern, SM, Alderman, MH. Sodium intake and mortality follow-up in the Third National Health and Nutrition Examination Survey (NHANES III). J Gen Intern Med. 2008. 23:1297–302 https://www.ncbi.nlm.nih.gov/pubmed/18465175 18465175 | Intervention/Exposure
78 | Colpani, V, Oppermann, K, Spritzer, PM. Causes of death and associated risk factors among climacteric women from Southern Brazil: a population based-study. BMC public health. 2014. 14:194 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L605937096 10.1186/1471-2458-14-194 24559309 | Intervention/Exposure
79 | Conrad, Z, Thomson, J, Jahns, L. Prospective Analysis of Vegetable Amount and Variety on the Risk of All-Cause and Cause-Specific Mortality among US Adults, 1999(-)2011. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30261669 | Intervention/Exposure
80 | Corella, D, Ramirez-Sabio, JB, Coltell, O, Ortega-Azorin, C, Estruch, R, Martinez-Gonzalez, MA, Salas-Salvado, J, Sorli, JV, Castaner, O, Aros, F, Garcia-Corte, FJ, Serra-Majem, L, Gomez-Gracia, E, Fiol, M, Pinto, X, Saez, GT, Toledo, E, Basora, J, Fito, M, Cofan, M, Ros, E, Ordovas, JM. Effects of the Ser326Cys Polymorphism in the DNA Repair OGG1 Gene on Cancer, Cardiovascular, and ACM in the PREDIMED Study: Modulation by Diet. J Acad Nutr Diet. 2018. 118:589–605 https://www.ncbi.nlm.nih.gov/pubmed/29305130 29305130 | Intervention/Exposure (data directly overlap with included article)
81 | Crowe, FL, Appleby, PN, Travis, RC, Key, TJ. Risk of hospitalization or death from ischemic heart disease among British vegetarians and nonvegetarians: Results from the EPIC-Oxford cohort study1-3. American Journal of Clinical Nutrition. 2013. 97:597–603 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L368405706. 10.3945/ajcn.112.044073 | Intervention/Exposure, Outcome
82 | Cummings, JR, Mason, AE, Puterman, E, Tomiyama, AJ. Comfort Eating and ACM in the US Health and Retirement Study. Int J Behav Med. 2018. 25:473–478 https://www.ncbi.nlm.nih.gov/pubmed/29243156 29243156 | Intervention/Exposure
83 | Dauchet, L, Jung, YJ. Association between vegetarian diets and chronic diseases: An epidemiological approach. Cahiers de Nutrition et de Dietetique. 2019. #volume#:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L2002637581 10.1016/j.cnd.2019.07.004 | Language
84 | Dehghan, M, Mente, A, Rangarajan, S, Sheridan, P, Mohan, V, Iqbal, R, Gupta, R, Lear, S, Wentzel-Viljoen, E, Avezum, A, Lopez-Jaramillo, P, Mony, P, Varma, RP, Kumar, R, Chifamba, J, Alhabib, KF, Mohammadifard, N, Oguz, A, Lanas, F, Rozanska, D, Bostrom, KB, Yusoff, K, Tsolkile, LP, Dans, A, Yusufali, A, Orlandini, A, Poirier, P, Khatib, R, Hu, B, Wei, L, Yin, L, Deeraili, A, Yeates, K, Yusuf, R, Ismail, N, Mozaffarian, D, Teo, K, Anand, SS, Yusuf, S. Association of dairy intake with cardiovascular disease and mortality in 21 countries from five continents (PURE): a prospective cohort study. Lancet. 2018. 392:2288–2297 https://www.ncbi.nlm.nih.gov/pubmed/30217460 30217460 | Intervention/Exposure
85 | Dehghan, M, Mente, A, Zhang, X, Swaminathan, S, Li, W, Mohan, V, Iqbal, R, Kumar, R, Wentzel-Viljoen, E, Rosengren, A, Amma, LI, Avezum, A, Chifamba, J, Diaz, R, Khatib, R, Lear, S, Lopez-Jaramillo, P, Liu, X, Gupta, R, Mohammadifard, N, Gao, N, Oguz, A, Ramli, AS, Seron, P, Sun, Y, Szuba, A, Tsolekile, L, Wielgosz, A, Yusuf, R, Hussein Yusufali, A, Teo, KK, Rangarajan, S, Dagenais, G, Bangdiwala, SI, Islam, S, Anand, SS, Yusuf, S. Associations of fats and carbohydrate intake with cardiovascular disease and mortality in 18 countries from five continents (PURE): a prospective cohort study. Lancet. 2017. 390:2050–2062 https://www.ncbi.nlm.nih.gov/pubmed/28864332 28864332 | Intervention/Exposure, Country
86 | deKoning, L, Anand, SS. Adherence to a Mediterranean diet and survival in a Greek population. Trichopoulou A, Costacou T, Bamia C, Trichopoulos D. N Engl J Med 2003; 348: 2599-608. Vasc Med. 2004. 9:145–6 https://www.ncbi.nlm.nih.gov/pubmed/15521707 15521707 | Study Design
87 | Deng, FE, Shivappa, N, Tang, Y, Mann, JR, Hebert, JR. Association between diet-related inflammation, all-cause, all-cancer, and cardiovascular disease mortality, with special focus on prediabetics: findings from NHANES III. Eur J Nutr. 2017. 56:1085–1093 https://www.ncbi.nlm.nih.gov/pubmed/26825592 26825592 | Intervention/Exposure
88 | Deschamps, V, Astier, X, Ferry, M, Rainfray, M, Emeriau, JP, Barberger-Gateau, P. Nutritional status of healthy elderly persons living in Dordogne, France, and relation with mortality and cognitive or functional decline. Eur J Clin Nutr. 2002. 56:305–12 https://www.ncbi.nlm.nih.gov/pubmed/11965506 11965506 | Intervention/Exposure
89 | DeSilvey, DL. Diet, lifestyle, mortality, and memory in the elderly. Am J Geriatr Cardiol. 2005. 14:41 https://www.ncbi.nlm.nih.gov/pubmed/15654154 15654154 | Study design, Publication Status
90 | Dilis, V, Katsoulis, M, Lagiou, P, Trichopoulos, D, Naska, A, Trichopoulou, A. Mediterranean diet and CHD: the Greek European Prospective Investigation into Cancer and Nutrition cohort. Br J Nutr. 2012. 108:699–709 https://www.ncbi.nlm.nih.gov/pubmed/22894912 22894912 | Outcome
91 | Ding, D, Rogers, K, van der Ploeg, H, Stamatakis, E, Bauman, AE. Traditional and Emerging Lifestyle Risk Behaviors and ACM in Middle-Aged and Older Adults: Evidence from a Large Population-Based Australian Cohort. PLoS Med. 2015. 12:e1001917 https://www.ncbi.nlm.nih.gov/pubmed/26645683 26645683 | Intervention/Exposure
92 | Dominguez, LJ, Bes-Rastrollo, M, Basterra-Gortari, FJ, Gea, A, Barbagallo, M, Martinez-Gonzalez, MA. Should we recommend reductions in saturated fat intake or in red/processed meat consumption? The SUN prospective cohort study. Clin Nutr. 2018. 37:1389–1398 https://www.ncbi.nlm.nih.gov/pubmed/28669669 28669669 | Intervention/Exposure
93 | Dominguez, LJ, Bes-Rastrollo, M, de la Fuente-Arrillaga, C, Toledo, E, Beunza, JJ, Barbagallo, M, Martinez-Gonzalez, MA. Similar prediction of total mortality, diabetes incidence and cardiovascular events using relative- and absolute-component Mediterranean diet score: the SUN cohort. Nutr Metab Cardiovasc Dis. 2013. 23:451–8 https://www.ncbi.nlm.nih.gov/pubmed/22402062 22402062 | Outcome
94 | Dominguez, LJ, Bes-Rastrollo, M, Toledo, E, Gea, A, Fresan, U, Barbagallo, M, Martinez-Gonzalez, MA. Dietary fiber intake and mortality in a Mediterranean population: the Seguimiento Universidad de Navarra (SUN) project. Eur J Nutr. 2018. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30367237 | Intervention/Exposure
95 | Dong, Y, Hao, G, Wang, Z, Wang, X, Chen, Z, Zhang, L. Ideal Cardiovascular Health Status and Risk of Cardiovascular Disease or ACM in Chinese Middle-Aged Population. Angiology. 2019. 70:523–529 https://www.ncbi.nlm.nih.gov/pubmed/30458624 30458624 | Intervention/Exposure
96 | Drake, I, Dias, JA, Teleka, S, Stocks, T, Orho-Melander, M. Lifestyle and cancer incidence and mortality risk depending on family history of cancer in two prospective cohorts. International Journal of Cancer. 2019. #volume#:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L627846423. 10.1002/ijc.32397 | Outcome
97 | Edwards, MK, Addoh, O, Loprinzi, PD. Predictive validity of the ACC/AHA pooled cohort equations in predicting residual-specific mortality in a national prospective cohort study of adults in the United States. Postgrad Med. 2016. 128:865–868 https://www.ncbi.nlm.nih.gov/pubmed/27701986 27701986 | Intervention/Exposure
98 | Edwards, MK, Shivappa, N, Mann, JR, Hebert, JR, Wirth, MD, Loprinzi, PD. The association between physical activity and dietary inflammatory index on mortality risk in U.S. adults. Phys Sportsmed. 2018. 46:249–254 https://www.ncbi.nlm.nih.gov/pubmed/29463180 29463180 | Intervention/Exposure
99 | Eguchi, E, Iso, H, Tanabe, N, Wada, Y, Yatsuya, H, Kikuchi, S, Inaba, Y, Tamakoshi, A. Healthy lifestyle behaviours and cardiovascular mortality among Japanese men and women: the Japan collaborative cohort study. Eur Heart J. 2012. 33:467–77 https://www.ncbi.nlm.nih.gov/pubmed/22334626 22334626 | Intervention/Exposure, Outcome
100 | Einvik, G, Klemsdal, TO, Sandvik, L, Hjerkinn, EM. A randomized clinical trial on n-3 polyunsaturated fatty acids supplementation and ACM in elderly men at high cardiovascular risk. Eur J Cardiovasc Prev Rehabil. 2010. 17:588–92 https://www.ncbi.nlm.nih.gov/pubmed/20389249 20389249 | Intervention/Exposure
101 | Emenaker, NJ, Vargas, AJ. The Mediterranean Diet, the OGG1 Gene, and Disease Risk: Early Evidence. J Acad Nutr Diet. 2018. 118:547–549 https://www.ncbi.nlm.nih.gov/pubmed/29305132 29305132 | Study design, Publication Status
102 | Estaquio, C, Castetbon, K, Kesse-Guyot, E, Bertrais, S, Deschamps, V, Dauchet, L, Peneau, S, Galan, P, Hercberg, S. The French National Nutrition and Health Program score is associated with nutritional status and risk of major chronic diseases. J Nutr. 2008. 138:946–53 https://www.ncbi.nlm.nih.gov/pubmed/18424606 18424606 | Intervention/Exposure, Outcome
103 | Estruch, R, MartÃ-nez-GonzÃ¡lez, MA. Mediterranean diets reduced cardiovascular events more than a low-fat diet in high-risk persons. Annals of Internal Medicine. 2013. 158:JC3 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L369142664. 10.7326/0003-4819-158-12-201306180-02003 | Study Design
104 | Etemadi, A, Sinha, R, Ward, MH, Graubard, BI, Inoue-Choi, M, Dawsey, SM, Abnet, CC. Mortality from different causes associated with meat, heme iron, nitrates, and nitrites in the NIH-AARP Diet and Health Study: population based cohort study. Bmj. 2017. 357:j1957 https://www.ncbi.nlm.nih.gov/pubmed/28487287 28487287 | Intervention/Exposure
105 | Farvid, MS, Malekshah, AF, Pourshams, A, Poustchi, H, Sepanlou, SG, Sharafkhah, M, Khoshnia, M, Farvid, M, Abnet, CC, Kamangar, F, Dawsey, SM, Brennan, P, Pharoah, PD, Boffetta, P, Willett, WC, Malekzadeh, R. Dietary Protein Sources and All-Cause and Cause-Specific Mortality: The Golestan Cohort Study in Iran. Am J Prev Med. 2017. 52:237–248 https://www.ncbi.nlm.nih.gov/pubmed/28109460 28109460 | Intervention/Exposure
106 | Fazel-Tabar Malekshah, A, Zaroudi, M, Etemadi, A, Islami, F, Sepanlou, S, Sharafkhah, M, Keshtkar, AA, Khademi, H, Poustchi, H, Hekmatdoost, A, Pourshams, A, Feiz Sani, A, Jafari, E, Kamangar, F, Dawsey, SM, Abnet, CC, Pharoah, PD, Berennan, PJ, Boffetta, P, Esmaillzadeh, A, Malekzadeh, R. The Combined Effects of Healthy Lifestyle Behaviors on ACM: The Golestan Cohort Study. Arch Iran Med. 2016. 19:752–761 https://www.ncbi.nlm.nih.gov/pubmed/27845543 27845543 | Intervention/Exposure
107 | Fiala, J, BrÃ¡zdovÃ¡, Z. A comparison between the lifestyles of men and women - Parents of school age children. Central European Journal of Public Health. 2000. 8:94–100 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L30255512 10857046 | Intervention/Exposure, Outcome
108 | Fidanza, F, Alberti, A, Lanti, M, Menotti, A. Mediterranean Adequacy Index: correlation with 25-year mortality from coronary heart disease in the Seven Countries Study. Nutr Metab Cardiovasc Dis. 2004. 14:254–8 https://www.ncbi.nlm.nih.gov/pubmed/15673059 15673059 | Study Design, Outcome
109 | Fillmore, KM, Stockwell, T, Chikritzhs, T, Bostrom, A, Kerr, W. Moderate Alcohol Use and Reduced Mortality Risk: Systematic Error in Prospective Studies and New Hypotheses. Annals of Epidemiology. 2007. 17:S16–S23 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L46671514 17478320 | Study Design, Intervention/Exposure
110 | Folsom, AR, Parker, ED, Harnack, LJ. Degree of concordance with DASH diet guidelines and incidence of hypertension and fatal cardiovascular disease. Am J Hypertens. 2007. 20:225–32 https://www.ncbi.nlm.nih.gov/pubmed/17324731 17324731 | Outcome
111 | Fortes, C, Forastiere, F, Farchi, S, Rapiti, E, Pastori, G, Perucci, CA. Diet and overall survival in a cohort of very elderly people. Epidemiology. 2000. 11:440–5 https://www.ncbi.nlm.nih.gov/pubmed/10874552 10874552 | Intervention/Exposure
112 | Fransen, HP, Beulens, JW, May, AM, Struijk, EA, Boer, JM, de Wit, GA, Onland-Moret, NC, van der Schouw, YT, Bueno-de-Mesquita, HB, Hoekstra, J, Peeters, PH. Dietary patterns in relation to quality-adjusted life years in the EPIC-NL cohort. Prev Med. 2015. 77:119–24 https://www.ncbi.nlm.nih.gov/pubmed/26007298 26007298 | Outcome
113 | Freedland, SJ. The effect of diet and supplements on prostate cancer. Clin Adv Hematol Oncol. 2014. 12:538–40 https://www.ncbi.nlm.nih.gov/pubmed/25356578 25356578 | Study Design
114 | Fresan, U, Martinez-Gonzalez, MA, Sabate, J, Bes-Rastrollo, M. Global sustainability (health, environment and monetary costs) of three dietary patterns: results from a Spanish cohort (the SUN project). BMJ Open. 2019. 9:e021541 https://www.ncbi.nlm.nih.gov/pubmed/30796113 | Outcome
115 | Fung, TT, Rexrode, KM, Mantzoros, CS, Manson, JE, Willett, WC, Hu, FB. Mediterranean diet and incidence of and mortality from coronary heart disease and stroke in women. Circulation. 2009. 119:1093–100 https://www.ncbi.nlm.nih.gov/pubmed/19221219 19221219 | Outcome
116 | Gage, TB, O’Connor, K. Nutrition and the variation in level and age patterns of mortality. 1994. Hum Biol. 2009. 81:551–74 https://www.ncbi.nlm.nih.gov/pubmed/20504181 20504181 | Intervention/Exposure, Publication Date
117 | Garcia-Arellano, A, Martinez-Gonzalez, MA, Ramallal, R, Salas-Salvado, J, Hebert, JR, Corella, D, Shivappa, N, Forga, L, Schroder, H, Munoz-Bravo, C, Estruch, R, Fiol, M, Lapetra, J, Serra-Majem, L, Ros, E, Rekondo, J, Toledo, E, Razquin, C, Ruiz-Canela, M. Dietary inflammatory index and ACM in large cohorts: The SUN and PREDIMED studies. Clin Nutr. 2019. 38:1221–1231 https://www.ncbi.nlm.nih.gov/pubmed/30651193 30651193 | Intervention/Exposure
118 | Gardener, H, Wright, CB, Gu, Y, Demmer, RT, Boden-Albala, B, Elkind, MS, Sacco, RL, Scarmeas, N. Mediterranean-style diet and risk of ischemic stroke, myocardial infarction, and vascular death: the Northern Manhattan Study. Am J Clin Nutr. 2011. 94:1458–64 https://www.ncbi.nlm.nih.gov/pubmed/22071704 22071704 | Outcome
119 | Gea, A, Bes-Rastrollo, M, Toledo, E, Garcia-Lopez, M, Beunza, JJ, Estruch, R, Martinez-Gonzalez, MA. Mediterranean alcohol-drinking pattern and mortality in the SUN (Seguimiento Universidad de Navarra) Project: a prospective cohort study. Br J Nutr. 2014. 111:1871–80 https://www.ncbi.nlm.nih.gov/pubmed/24480368 24480368 | Intervention/Exposure
120 | Gomez de la Camara, A, De Andres Esteban, E, Urrutia Cuchi, G, Calderon Sandubete, E, Rubio Herrera, MA, Menendez Orenga, M, Lora Pablos, D. Variability of nutrients intake, lipid profile and cardiovascular mortality among geographical areas in Spain: The DRECE study. Geospat Health. 2017. 12:524 https://www.ncbi.nlm.nih.gov/pubmed/29239557 29239557 | Intervention/Exposure, Outcome
121 | Gonzalez, S, Huerta, JM, Fernandez, S, Patterson, AM, Lasheras, C. Differences in overall mortality in the elderly may be explained by diet. Gerontology. 2008. 54:232–7 https://www.ncbi.nlm.nih.gov/pubmed/18503250 18503250 | Intervention/Exposure
122 | Gopinath, B, Buyken, AE, Flood, VM, Empson, M, Rochtchina, E, Mitchell, P. Consumption of polyunsaturated fatty acids, fish, and nuts and risk of inflammatory disease mortality. Am J Clin Nutr. 2011. 93:1073–9 https://www.ncbi.nlm.nih.gov/pubmed/21411616 21411616 | Intervention/Exposure, Outcome
123 | Gopinath, B, Flood, VM, Burlutksy, G, Mitchell, P. Consumption of nuts and risk of total and cause-specific mortality over 15 years. Nutr Metab Cardiovasc Dis. 2015. 25:1125–31 https://www.ncbi.nlm.nih.gov/pubmed/26607701 26607701 | Intervention/Exposure
124 | Gopinath, B, Flood, VM, Kifley, A, Louie, JC, Mitchell, P. Association Between Carbohydrate Nutrition and Successful Aging Over 10 Years. J Gerontol A Biol Sci Med Sci. 2016. 71:1335–40 https://www.ncbi.nlm.nih.gov/pubmed/27252308 27252308 | Intervention/Exposure
125 | Graffouillere, L, Deschasaux, M, Mariotti, F, Neufcourt, L, Shivappa, N, Hebert, JR, Wirth, MD, Latino-Martel, P, Hercberg, S, Galan, P, Julia, C, Kesse-Guyot, E, Touvier, M. Prospective association between the Dietary Inflammatory Index and mortality: modulation by antioxidant supplementation in the SU.VI.MAX randomized controlled trial. Am J Clin Nutr. 2016. 103:878–85 https://www.ncbi.nlm.nih.gov/pubmed/26864363 26864363 | Intervention/Exposure
126 | Grech, A, Sui, Z, Siu, HY, Zheng, M, Allman-Farinelli, M, Rangan, A. Socio-Demographic Determinants of Diet Quality in Australian Adults Using the Validated Healthy Eating Index for Australian Adults (HEIFA-2013). Healthcare (Basel). 2017. 5:#pages# https://www.ncbi.nlm.nih.gov/pubmed/28165394 | Study Design, Outcome
127 | Greenlee, H, Strizich, G, Lovasi, GS, Kaplan, RC, Biggs, ML, Li, CI, Richardson, J, Burke, GL, Fitzpatrick, AL, Fretts, AM, Psaty, BM, Fried, LP. Concordance With Prevention Guidelines and Subsequent Cancer, Cardiovascular Disease, and Mortality: A Longitudinal Study of Older Adults. Am J Epidemiol. 2017. 186:1168–1179 https://www.ncbi.nlm.nih.gov/pubmed/29020206 29020206 | Intervention/Exposure
128 | Guasch-Ferre, M, Babio, N, Martinez-Gonzalez, MA, Corella, D, Ros, E, Martin-Pelaez, S, Estruch, R, Aros, F, Gomez-Gracia, E, Fiol, M, Santos-Lozano, JM, Serra-Majem, L, Bullo, M, Toledo, E, Barragan, R, Fito, M, Gea, A, Salas-Salvado, J. Dietary fat intake and risk of cardiovascular disease and ACM in a population at high risk of cardiovascular disease. Am J Clin Nutr. 2015. 102:1563–73 https://www.ncbi.nlm.nih.gov/pubmed/26561617 26561617 | Intervention/Exposure
129 | Guasch-Ferre, M, Bullo, M, Estruch, R, Corella, D, Martinez-Gonzalez, MA, Ros, E, Covas, M, Aros, F, Gomez-Gracia, E, Fiol, M, Lapetra, J, Munoz, MA, Serra-Majem, L, Babio, N, Pinto, X, Lamuela-Raventos, RM, Ruiz-Gutierrez, V, Salas-Salvado, J. Dietary magnesium intake is inversely associated with mortality in adults at high cardiovascular disease risk. J Nutr. 2014. 144:55–60 https://www.ncbi.nlm.nih.gov/pubmed/24259558 24259558 | Intervention/Exposure
130 | Guasch-Ferre, M, Bullo, M, Martinez-Gonzalez, MA, Corella, D, Ros, E, Estruch, R, Warnberg, J, Serra-Majem, L, Basora, J, Salas-Salvado, J. Frequency of nut consumption and risk of total mortality in the predimed study. Annals of nutrition and metabolism.. 2013. 62:17–18 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01027080/full | Study Design, Intervention/Exposure, Publication Status
131 | Guasch-Ferre, M, Bullo, M, Martinez-Gonzalez, MA, Ros, E, Corella, D, Estruch, R, Fito, M, Aros, F, Warnberg, J, Fiol, M, Lapetra, J, Vinyoles, E, Lamuela-Raventos, RM, Serra-Majem, L, Pinto, X, Ruiz-Gutierrez, V, Basora, J, Salas-Salvado, J. Frequency of nut consumption and mortality risk in the PREDIMED nutrition intervention trial. BMC Med. 2013. 11:164 https://www.ncbi.nlm.nih.gov/pubmed/23866098 23866098 | Intervention/Exposure
132 | Guasch-Ferre, M, Hu, FB, Martinez-Gonzalez, MA, Fito, M, Bullo, M, Estruch, R, Ros, E, Corella, D, Recondo, J, Gomez-Gracia, E, Fiol, M, Lapetra, J, Serra-Majem, L, Munoz, MA, Pinto, X, Lamuela-Raventos, RM, Basora, J, Buil-Cosiales, P, Sorli, JV, Ruiz-Gutierrez, V, Martinez, JA, Salas-Salvado, J. Olive oil intake and risk of cardiovascular disease and mortality in the PREDIMED Study. BMC Med. 2014. 12:78 https://www.ncbi.nlm.nih.gov/pubmed/24886626 24886626 | Intervention/Exposure
133 | Guasch-Ferre, M, Salas-Salvado, J, Ros, E, Estruch, R, Corella, D, Fito, M, Martinez-Gonzalez, MA. The PREDIMED trial, Mediterranean diet and health outcomes: How strong is the evidence?. Nutr Metab Cardiovasc Dis. 2017. 27:624–632 https://www.ncbi.nlm.nih.gov/pubmed/28684083 28684083 | Study Design
134 | Guasch-Ferre, M, Zong, G, Willett, WC, Zock, PL, Wanders, AJ, Hu, FB, Sun, Q. Associations of Monounsaturated Fatty Acids From Plant and Animal Sources With Total and Cause-Specific Mortality in Two US Prospective Cohort Studies. Circ Res. 2019. 124:1266–1275 https://www.ncbi.nlm.nih.gov/pubmed/30689516 30689516 | Intervention/Exposure
135 | Guenard, F, Bouchard-Mercier, A, Rudkowska, I, Lemieux, S, Couture, P, Vohl, MC. Genome-Wide Association Study of Dietary Pattern Scores. Nutrients. 2017. 9:#pages# https://www.ncbi.nlm.nih.gov/pubmed/28644415 | Intervention/Exposure, Outcome
136 | Guinter, MA, McCullough, ML, Gapstur, SM, Campbell, PT. Associations of Pre- and Postdiagnosis Diet Quality With Risk of Mortality Among Men and Women With Colorectal Cancer. J Clin Oncol. 2018. #volume#:Jco1800714 https://www.ncbi.nlm.nih.gov/pubmed/30339519 30339519 | Health Status
137 | Guzman-Castillo, M, Ahmed, R, Hawkins, N. Correction. The contribution of primary prevention medication and dietary change in coronary mortality reduction in England between 2000 and 2007: a modelling study. BMJ Open. 2015. 5:e006070corr1 https://www.ncbi.nlm.nih.gov/pubmed/25869681 | Study design, Publication Status
138 | Gwynne, M, Mounsey, A. Mediterranean diet: Higher fat but lower risk. Journal of Family Practice. 2013. 62:745–748 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L370406814 | Study Design, Outcome
139 | HÃ¥glin, L, LundstrÃ¶m, S, Kaati, G, BÃ¤ckman, L, Bygren, LO. ACM of patients with dyslipidemia up to 19 years after a multidisciplinary lifestyle modification programme: A randomized trial. European Journal of Cardiovascular Prevention and Rehabilitation. 2011. 18:79–85 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L51028780 10.1097/HJR.0b013e32833a65cc 20700054 | Intervention/Exposure, Health Status
140 | Halpern, LW. Eating Whole Grains Can Reduce Disease and Mortality Risks. Am J Nurs. 2016. 116:15 https://www.ncbi.nlm.nih.gov/pubmed/27560322 | Study Design
141 | Hara, M, Mori, M, Shono, N, Higaki, Y, Nishizumi, M. Lifestyle-related risk factors for total and cancer mortality in men and women. Environ Health Prev Med. 2000. 5:90–6 https://www.ncbi.nlm.nih.gov/pubmed/21432191 21432191 | Intervention/Exposure
142 | Harris, WS, Von Schacky, C. The Omega-3 Index: a new risk factor for death from coronary heart disease?. Prev Med. 2004. 39:212–20 https://www.ncbi.nlm.nih.gov/pubmed/15208005 15208005 | Intervention/Exposure, Outcome
143 | Harriss, LR, English, DR, Powles, J, Giles, GG, Tonkin, AM, Hodge, AM, Brazionis, L, O’Dea, K. Dietary patterns and cardiovascular mortality in the Melbourne Collaborative Cohort Study. Am J Clin Nutr. 2007. 86:221–9 https://www.ncbi.nlm.nih.gov/pubmed/17616784 17616784 | Outcome
144 | Harvey Anderson, G, Wong, CL. Dietary patterns, food composition and chronic disease. Clinica e Investigacion en Arteriosclerosis. 2010. 22:6–9 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L361246399 10.1016/S0214-9168(10)70025-5 | Study Design
145 | Hastert, TA, Beresford, SA, Sheppard, L, White, E. Adherence to the WCRF/AICR cancer prevention recommendations and cancer-specific mortality: results from the Vitamins and Lifestyle (VITAL) Study. Cancer Causes Control. 2014. 25:541–52 https://www.ncbi.nlm.nih.gov/pubmed/24557428 24557428 | Intervention/Exposure, Outcome
146 | Haupt, TH, Rasmussen, LJH, Kallemose, T, Ladelund, S, Andersen, O, Pisinger, C, Eugen-Olsen, J. Healthy lifestyles reduce suPAR and mortality in a Danish general population study. Immun Ageing. 2019. 16:1 https://www.ncbi.nlm.nih.gov/pubmed/30679937 30679937 | Intervention/Exposure
147 | Heitz, AE, Baumgartner, RN, Baumgartner, KB, Boone, SD. Healthy lifestyle impact on breast cancer-specific and ACM. Breast Cancer Res Treat. 2018. 167:171–181 https://www.ncbi.nlm.nih.gov/pubmed/28861753 28861753 | Intervention/Exposure
148 | Helis, E, Augustincic, L, Steiner, S, Chen, L, Turton, P, Fodor, JG. Time trends in cardiovascular and ACM in the ‘old’ and ‘new’ European Union countries. Eur J Cardiovasc Prev Rehabil. 2011. 18:347–59 https://www.ncbi.nlm.nih.gov/pubmed/21450659 21450659 | Study Design, Intervention/Exposure
149 | Henriquez-Sanchez, P, Sanchez-Villegas, A, Ruano-Rodriguez, C, Gea, A, Lamuela-Raventos, RM, Estruch, R, Salas-Salvado, J, Covas, MI, Corella, D, Schroder, H, Gutierrez-Bedmar, M, Santos-Lozano, JM, Pinto, X, Aros, F, Fiol, M, Tresserra-Rimbau, A, Ros, E, Martinez-Gonzalez, MA, Serra-Majem, L. Dietary total antioxidant capacity and mortality in the PREDIMED study. Eur J Nutr. 2016. 55:227–36 https://www.ncbi.nlm.nih.gov/pubmed/25663609 25663609 | Intervention/Exposure
150 | Hernandez-Hernandez, A, Gea, A, Ruiz-Canela, M, Toledo, E, Beunza, JJ, Bes-Rastrollo, M, Martinez-Gonzalez, MA. Mediterranean Alcohol-Drinking Pattern and the Incidence of Cardiovascular Disease and Cardiovascular Mortality: The SUN Project. Nutrients. 2015. 7:9116–26 https://www.ncbi.nlm.nih.gov/pubmed/26556367 26556367 | Intervention/Exposure
151 | Hibbeln, JR, Nieminen, LR, Blasbalg, TL, Riggs, JA, Lands, WE. Healthy intakes of n-3 and n-6 fatty acids: estimations considering worldwide diversity. Am J Clin Nutr. 2006. 83:1483s–1493s https://www.ncbi.nlm.nih.gov/pubmed/16841858 16841858 | Intervention/Exposure
152 | Hjerkinn, EM, Sandvik, L, Hjermann, I, Arnesen, H. Effect of diet intervention on long-term mortality in healthy middle-aged men with combined hyperlipidaemia. Journal of Internal Medicine. 2004. 255:68–73 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L38121923 10.1046/j.0954-6820.2003.01248.x 14687240 | Health Status
153 | Holme, I, Retterstol, K, Norum, KR, Hjermann, I. Lifelong benefits on myocardial infarction mortality: 40-year follow-up of the randomized Oslo diet and antismoking study. J Intern Med. 2016. 280:221–7 https://www.ncbi.nlm.nih.gov/pubmed/26924204 26924204 | Intervention/Exposure
154 | Hshieh, TT, Petrone, AB, Gaziano, JM, Djousse, L. Nut consumption and risk of mortality in the Physicians’ Health Study. Am J Clin Nutr. 2015. 101:407–12 https://www.ncbi.nlm.nih.gov/pubmed/25646339 25646339 | Intervention/Exposure
155 | Huang, T, Xu, M, Lee, A, Cho, S, Qi, L. Consumption of whole grains and cereal fiber and total and cause-specific mortality: prospective analysis of 367,442 individuals. BMC Med. 2015. 13:59 https://www.ncbi.nlm.nih.gov/pubmed/25858689 25858689 | Intervention/Exposure
156 | Huang, X, Jimenez-Moleon, JJ, Lindholm, B, Cederholm, T, Arnlov, J, Riserus, U, Sjogren, P, Carrero, JJ. Mediterranean diet, kidney function, and mortality in men with CKD. Clin J Am Soc Nephrol. 2013. 8:1548–55 https://www.ncbi.nlm.nih.gov/pubmed/23744002 23744002 | Health Status
157 | Huang, YC, Wahlqvist, ML, Kao, MD, Wang, JL, Lee, MS. Optimal Dietary and Plasma Magnesium Statuses Depend on Dietary Quality for a Reduction in the Risk of ACM in Older Adults. Nutrients. 2015. 7:5664–83 https://www.ncbi.nlm.nih.gov/pubmed/26184299 26184299 | Intervention/Exposure
158 | Huang, YC, Wahlqvist, ML, Lee, MS. Appetite predicts mortality in free-living older adults in association with dietary diversity. A NAHSIT cohort study. Appetite. 2014. 83:89–96 https://www.ncbi.nlm.nih.gov/pubmed/25131903 25131903 | Intervention/Exposure
159 | Huang, YC, Wahlqvist, ML, Lo, YTC, Lin, C, Chang, HY, Lee, MS. A non-invasive modifiable Healthy Ageing Nutrition Index (HANI) predicts longevity in free-living older Taiwanese. Scientific reports. 2018. 8:7113 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L629354978 10.1038/s41598-018-24625-3 29739965 | Intervention/Exposure
160 | Hung, JD, Murray, SW, Shaw, MA, Unwin, D. Impact of a low carbohydrate diet on traditional CVD risk factors in people with features of the metabolic syndrome and type 2 diabetes. European journal of preventive cardiology. 2018. 25:S14–S15 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01620675/full | Study design, Publication Status
161 | Hutchinson, L. Prevention: Low-fat diet linked to decline in breast cancer mortality. Nat Rev Clin Oncol. 2017. 14:526 https://www.ncbi.nlm.nih.gov/pubmed/28719583 | Study Design
162 | Iff, S, Wong, G, Webster, AC, Flood, V, Wang, JJ, Mitchell, P, Craig, JC. Relative energy balance, CKD, and risk of cardiovascular and ACM. Am J Kidney Dis. 2014. 63:437–45 https://www.ncbi.nlm.nih.gov/pubmed/24210588 24210588 | Intervention/Exposure, Health Status
163 | Iimuro, S, Yoshimura, Y, Umegaki, H, Sakurai, T, Araki, A, Ohashi, Y, Iijima, K, Ito, H. Dietary pattern and mortality in Japanese elderly patients with type 2 diabetes mellitus: does a vegetable- and fish-rich diet improve mortality? An explanatory study. Geriatr Gerontol Int. 2012. 12 Suppl 1:59–67 https://www.ncbi.nlm.nih.gov/pubmed/22435941 | Health Status
164 | Ilic, M, Ilic, I, Stojanovic, G, Zivanovic-Macuzic, I. Association of the consumption of common food groups and beverages with mortality from cancer, ischaemic heart disease and diabetes mellitus in Serbia, 1991-2010: an ecological study. BMJ Open. 2016. 6:e008742 https://www.ncbi.nlm.nih.gov/pubmed/26733565 | Study Design, Outcome
165 | Inoue-Choi, M, Robien, K, Lazovich, D. Adherence to the WCRF/AICR guidelines for cancer prevention is associated with lower mortality among older female cancer survivors. Cancer Epidemiol Biomarkers Prev. 2013. 22:792–802 https://www.ncbi.nlm.nih.gov/pubmed/23462914 23462914 | Intervention/Exposure, Health Status
166 | Isiozor, NM, Kunutsor, SK, Voutilainen, A, Kurl, S, Kauhanen, J, Laukkanen, JA. American heart association’s cardiovascular health metrics and risk of cardiovascular disease mortality among a middle-aged male Scandinavian population. Annals of Medicine. 2019. 51:306–313 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L628528307 10.1080/07853890.2019.1639808 31264909 | Outcome
167 | Iso, H, Kubota, Y. Nutrition and disease in the Japan Collaborative Cohort Study for Evaluation of Cancer (JACC). Asian Pac J Cancer Prev. 2007. 8 Suppl:35–80 https://www.ncbi.nlm.nih.gov/pubmed/18260705 18260705 | Study Design, Intervention/Exposure
168 | Ivey, KL, Jensen, MK, Hodgson, JM, Eliassen, AH, Cassidy, A, Rimm, EB. Association of flavonoid-rich foods and flavonoids with risk of ACM. Br J Nutr. 2017. 117:1470–1477 https://www.ncbi.nlm.nih.gov/pubmed/28606222 28606222 | Intervention/Exposure, Outcome
169 | Jacobs, S, Harmon, BE, Ollberding, NJ, Wilkens, LR, Monroe, KR, Kolonel, LN, Le Marchand, L, Boushey, CJ, Maskarinec, G. Among 4 Diet Quality Indexes, Only the Alternate Mediterranean Diet Score Is Associated with Better Colorectal Cancer Survival and Only in African American Women in the Multiethnic Cohort. J Nutr. 2016. 146:1746–55 https://www.ncbi.nlm.nih.gov/pubmed/27511927 27511927 | Health Status
170 | Jankovic, N, Geelen, A, Streppel, MT, de Groot, LC, Kiefte-de Jong, JC, Orfanos, P, Bamia, C, Trichopoulou, A, Boffetta, P, Bobak, M, Pikhart, H, Kee, F, O’Doherty, MG, Buckland, G, Woodside, J, Franco, OH, Ikram, MA, Struijk, EA, Pajak, A, Malyutina, S, Kubinova, R, Wennberg, M, Park, Y, Bueno-de-Mesquita, HB, Kampman, E, Feskens, EJ. WHO guidelines for a healthy diet and mortality from cardiovascular disease in European and American elderly: the CHANCES project. Am J Clin Nutr. 2015. 102:745–56 https://www.ncbi.nlm.nih.gov/pubmed/26354545 26354545 | Study Design, Outcome
171 | Jankovic, N, Geelen, A, Streppel, MT, de Groot, LC, Orfanos, P, van den Hooven, EH, Pikhart, H, Boffetta, P, Trichopoulou, A, Bobak, M, Bueno-de-Mesquita, HB, Kee, F, Franco, OH, Park, Y, Hallmans, G, Tjonneland, A, May, AM, Pajak, A, Malyutina, S, Kubinova, R, Amiano, P, Kampman, E, Feskens, EJ. Adherence to a healthy diet according to the World Health Organization guidelines and ACM in elderly adults from Europe and the United States. Am J Epidemiol. 2014. 180:978–88 https://www.ncbi.nlm.nih.gov/pubmed/25318818 25318818 | Study design,
172 | Jayanama, K, Theou, O, Blodgett, JM, Cahill, L, Rockwood, K. Frailty, nutrition-related parameters, and mortality across the adult age spectrum. BMC Med. 2018. 16:188 https://www.ncbi.nlm.nih.gov/pubmed/30360759 30360759 | Intervention/Exposure, Outcome
173 | Johansson, I, Nilsson, LM, Esberg, A, Jansson, JH, Winkvist, A. Dairy intake revisited - associations between dairy intake and lifestyle related cardio-metabolic risk factors in a high milk consuming population. Nutr J. 2018. 17:110 https://www.ncbi.nlm.nih.gov/pubmed/30466440 30466440 | Intervention/Exposure, Outcome
174 | Juanola-Falgarona, M, Salas-Salvado, J, Martinez-Gonzalez, MA, Corella, D, Estruch, R, Ros, E, Fito, M, Aros, F, Gomez-Gracia, E, Fiol, M, Lapetra, J, Basora, J, Lamuela-Raventos, RM, Serra-Majem, L, Pinto, X, Munoz, MA, Ruiz-Gutierrez, V, Fernandez-Ballart, J, Bullo, M. Dietary intake of vitamin K is inversely associated with mortality risk. J Nutr. 2014. 144:743–50 https://www.ncbi.nlm.nih.gov/pubmed/24647393 24647393 | Intervention/Exposure
175 | Juel, K, SÃ¸rensen, J, BrÃ¸nnum-Hansen, H. Risk factors and public health in Denmark. Scandinavian journal of public health. 2008. 36 Suppl 1:11–227 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L550155648 | Study Design
176 | Kane-Diallo, A, Srour, B, Sellem, L, Deschasaux, M, Latino-Martel, P, Hercberg, S, Galan, P, Fassier, P, GuÃ©raud, F, Pierre, FH, Kesse-Guyot, E, AllÃ¨s, B, Touvier, M. Association between a pro plant-based dietary score and cancer risk in the prospective NutriNet-santÃ© cohort. International Journal of Cancer. 2018. 143:2168–2176 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L623882304 10.1002/ijc.31593 29752709 | Outcome
177 | Kant, AK, Graubard, BI. A prospective study of frequency of eating restaurant prepared meals and subsequent 9-year risk of all-cause and cardiometabolic mortality in US adults. PLoS One. 2018. 13:e0191584 https://www.ncbi.nlm.nih.gov/pubmed/29360850 29360850 | Intervention/Exposure
178 | Kee, CC, Sumarni, MG, Lim, KH, Selvarajah, S, Haniff, J, Tee, GHH, Gurpreet, K, Faudzi, YA, Amal, NM. Association of BMI with risk of CVD mortality and ACM. Public Health Nutr. 2017. 20:1226–1234 https://www.ncbi.nlm.nih.gov/pubmed/28077198 28077198 | Intervention/Exposure
179 | Keller, HH, Ostbye, T. Nutritional risk and time to death; predictive validity of SCREEN (Seniors in the Community Risk Evaluation for Eating and Nutrition). J Nutr Health Aging. 2003. 7:274–9 https://www.ncbi.nlm.nih.gov/pubmed/12917754 12917754 | Intervention/Exposure
180 | Kenfield, SA, DuPre, N, Richman, EL, Stampfer, MJ, Chan, JM, Giovannucci, EL. Mediterranean diet and prostate cancer risk and mortality in the Health Professionals Follow-up Study. Eur Urol. 2014. 65:887–94 https://www.ncbi.nlm.nih.gov/pubmed/23962747 23962747 | Health Status
181 | Kesse-Guyot, E, Touvier, M, Henegar, A, Czernichow, S, Galan, P, Hercberg, S, Castetbon, K. Higher adherence to French dietary guidelines and chronic diseases in the prospective SU.VI.MAX cohort. Eur J Clin Nutr. 2011. 65:887–94 https://www.ncbi.nlm.nih.gov/pubmed/21559045 21559045 | Intervention/Exposure
182 | Kiage, JN, Sampson, UK, Lipworth, L, Fazio, S, Mensah, GA, Yu, Q, Munro, H, Akwo, EA, Dai, Q, Blot, WJ, Kabagambe, EK. Intake of polyunsaturated fat in relation to mortality among statin users and non-users in the Southern Community Cohort Study. Nutr Metab Cardiovasc Dis. 2015. 25:1016–24 https://www.ncbi.nlm.nih.gov/pubmed/26298428 26298428 | Intervention/Exposure
183 | Kim, K, Vance, TM, Chen, MH, Chun, OK. Dietary total antioxidant capacity is inversely associated with all-cause and cardiovascular disease death of US adults. Eur J Nutr. 2018. 57:2469–2476 https://www.ncbi.nlm.nih.gov/pubmed/28791462 28791462 | Intervention/Exposure
184 | Kmietowicz, Z. Fried food linked to increased risk of death among older US women. Bmj. 2019. 364:l362 https://www.ncbi.nlm.nih.gov/pubmed/30679173 30679173 | Study Design, Intervention/Exposure
185 | Kobayashi, M, Sasazuki, S, Shimazu, T, Sawada, N, Yamaji, T, Iwasaki, M, Mizoue, T, Tsugane, S. Association of dietary diversity with total mortality and major causes of mortality in the Japanese population: JPHC study. Eur J Clin Nutr. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30890778 | Intervention/Exposure
186 | Kondo, K, Miura, K, Tanaka-Mizuno, S, Kadota, A, Arima, H, Okuda, N, Fujiyoshi, A, Miyagawa, N, Yoshita, K, Okamura, T, Okayama, A, Ueshima, H. Cardiovascular Risk Assessment Chart by Dietary Factors in Japan- NIPPON DATA80. Circ J. 2019. 83:1254–1260 https://www.ncbi.nlm.nih.gov/pubmed/31006729 31006729 | Intervention/Exposure, Outcome
187 | Krokstad, S, Ding, D, Grunseit, AC, Sund, ER, Holmen, TL, Rangul, V, Bauman, A. Multiple lifestyle behaviours and mortality, findings from a large population-based Norwegian cohort study - The HUNT Study. BMC Public Health. 2017. 17:58 https://www.ncbi.nlm.nih.gov/pubmed/28068991 28068991 | Intervention/Exposure, Outcome,
188 | Kromhout, D, Menotti, A, Alberti-Fidanza, A, Puddu, PE, Hollman, P, Kafatos, A, Tolonen, H, Adachi, H, Jacobs, DR, Jr. Comparative ecologic relationships of saturated fat, sucrose, food groups, and a Mediterranean food pattern score to 50-year coronary heart disease mortality rates among 16 cohorts of the Seven Countries Study. Eur J Clin Nutr. 2018. 72:1103–1110 https://www.ncbi.nlm.nih.gov/pubmed/29769748 29769748 | Outcome
189 | Lagiou, P, Sandin, S, Weiderpass, E, Lagiou, A, Mucci, L, Trichopoulos, D, Adami, HO. Low carbohydrate-high protein diet and mortality in a cohort of Swedish women. J Intern Med. 2007. 261:366–74 https://www.ncbi.nlm.nih.gov/pubmed/17391111 17391111 | Intervention/Exposure (did not describe the macronutrient distribution of the diet for the categories analyzed)
190 | Lee, JE, McLerran, DF, Rolland, B, Chen, Y, Grant, EJ, Vedanthan, R, Inoue, M, Tsugane, S, Gao, YT, Tsuji, I, Kakizaki, M, Ahsan, H, Ahn, YO, Pan, WH, Ozasa, K, Yoo, KY, Sasazuki, S, Yang, G, Watanabe, T, Sugawara, Y, Parvez, F, Kim, DH, Chuang, SY, Ohishi, W, Park, SK, Feng, Z, Thornquist, M, Boffetta, P, Zheng, W, Kang, D, Potter, J, Sinha, R. Meat intake and cause-specific mortality: a pooled analysis of Asian prospective cohort studies. Am J Clin Nutr. 2013. 98:1032–41 https://www.ncbi.nlm.nih.gov/pubmed/23902788 23902788 | Intervention/Exposure
191 | Lee, MS, Huang, YC, Su, HH, Lee, MZ, Wahlqvist, ML. A simple food quality index predicts mortality in elderly Taiwanese. J Nutr Health Aging. 2011. 15:815–21 https://www.ncbi.nlm.nih.gov/pubmed/22159767 22159767 | Country
192 | Lee, PH, Chan, CW. Energy intake, energy required and mortality in an older population. Public Health Nutr. 2016. 19:3178–3184 https://www.ncbi.nlm.nih.gov/pubmed/27406257 27406257 | Intervention/Exposure
193 | Lelli, D, Antonelli Incalzi, R, Ferrucci, L, Bandinelli, S, Pedone, C. Association between PUFA intake and serum concentration and mortality in older adults: A cohort study. Clin Nutr. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30850268 | Intervention/Exposure
194 | Lelli, D, Antonelli-Incalzi, R, Bandinelli, S, Ferrucci, L, Pedone, C. Association Between Sodium Excretion and Cardiovascular Disease and Mortality in the Elderly: A Cohort Study. Journal of the American Medical Directors Association. 2018. 19:229–234 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L618787413 10.1016/j.jamda.2017.09.004 29042264 | Intervention/Exposure
195 | Letois, F, Mura, T, Scali, J, Gutierrez, LA, Feart, C, Berr, C. Nutrition and mortality in the elderly over 10 years of follow-up: the Three-City study. Br J Nutr. 2016. 116:882–9 https://www.ncbi.nlm.nih.gov/pubmed/27452277 27452277 | Intervention/Exposure
196 | Levey, AS, Greene, T, Sarnak, MJ, Wang, X, Beck, GJ, Kusek, JW, Collins, A, Kopple, JD. The effect of very low protein diet on progression of kidney disease and mortality in Modification of Diet in Renal Disease Study B. Journal of the american society of nephrology : JASN. 2004. 15:586A https://www.cochranelibrary.com/central/doi/10.1002/central/CN-00550761/full | Study design, Publication Status
197 | Levine, ME, Suarez, JA, Brandhorst, S, Balasubramanian, P, Cheng, CW, Madia, F, Fontana, L, Mirisola, MG, Guevara-Aguirre, J, Wan, J, Passarino, G, Kennedy, BK, Wei, M, Cohen, P, Crimmins, EM, Longo, VD. Low protein intake is associated with a major reduction in IGF-1, cancer, and overall mortality in the 65 and younger but not older population. Cell Metab. 2014. 19:407–17 https://www.ncbi.nlm.nih.gov/pubmed/24606898 24606898 | Intervention/Exposure
198 | Levitan, EB, Mittleman, MA, Wolk, A. Dietary glycemic index, dietary glycemic load and mortality among men with established cardiovascular disease. Eur J Clin Nutr. 2009. 63:552–7 https://www.ncbi.nlm.nih.gov/pubmed/18091767 18091767 | Health Status
199 | Li, G, Zhang, P, Wang, J, An, Y, Gong, Q, Gregg, EW, Yang, W, Zhang, B, Shuai, Y, Hong, J, ,. Cardiovascular mortality, ACM, and diabetes incidence after lifestyle intervention for people with impaired glucose tolerance in the Da Qing Diabetes Prevention Study: a 23-year follow-up study. The lancet. Diabetes & endocrinology. 2014. 2:474–480 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01001566/full 24731674 | Intervention/Exposure, Health Status
200 | Li, K, Husing, A, Kaaks, R. Lifestyle risk factors and residual life expectancy at age 40: a German cohort study. BMC Med. 2014. 12:59 https://www.ncbi.nlm.nih.gov/pubmed/24708705 24708705 | Intervention/Exposure
201 | Li, S, Chiuve, SE, Flint, A, Pai, JK, Forman, JP, Hu, FB, Willett, WC, Mukamal, KJ, Rimm, EB. Better diet quality and decreased mortality among myocardial infarction survivors. JAMA Intern Med. 2013. 173:1808–18 https://www.ncbi.nlm.nih.gov/pubmed/23999993 23999993 | Health Status
202 | Li, S, Flint, A, Pai, JK, Forman, JP, Hu, FB, Willett, WC, Rexrode, KM, Mukamal, KJ, Rimm, EB. Dietary fiber intake and mortality among survivors of myocardial infarction: Prospective cohort study OPEN ACCESS. BMJ (Online). 2014. 348:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L372982678 | Intervention/Exposure
203 | Li, S, Flint, A, Pai, JK, Forman, JP, Hu, FB, Willett, WC, Rexrode, KM, Mukamal, KJ, Rimm, EB. Low carbohydrate diet from plant or animal sources and mortality among myocardial infarction survivors. J Am Heart Assoc. 2014. 3:e001169 https://www.ncbi.nlm.nih.gov/pubmed/25246449 25246449 | Health Status
204 | Li, Y, Pan, A, Wang, DD, Liu, X, Dhana, K, Franco, OH, Kaptoge, S, Di Angelantonio, E, Stampfer, M, Willett, WC, Hu, FB. Impact of Healthy Lifestyle Factors on Life Expectancies in the US Population. Circulation. 2018. 138:345–355 https://www.ncbi.nlm.nih.gov/pubmed/29712712 29712712 | Intervention/Exposure
205 | Liese, AD, Krebs-Smith, SM, Subar, AF, George, SM, Harmon, BE, Neuhouser, ML, Boushey, CJ, Schap, TE, Reedy, J. The dietary patterns methods project: Synthesis of findings across cohorts and relevance to dietary guidance. Journal of Nutrition. 2015. 145:393–402 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L604030004 | Study Design
206 | Lilamand, M, Kelaiditi, E, Demougeot, L, Rolland, Y, Vellas, B, Cesari, M. The Mini Nutritional Assessment-Short Form and mortality in nursing home residents-results from the INCUR study. J Nutr Health Aging. 2015. 19:383–8 https://www.ncbi.nlm.nih.gov/pubmed/25809801 25809801 | Intervention/Exposure
207 | Lim, CC, Hayes, RB, Ahn, J, Shao, Y, Silverman, DT, Jones, RR, Thurston, GD. Mediterranean Diet and the Association Between Air Pollution and Cardiovascular Disease Mortality Risk. Circulation. 2019. 139:1766–1775 https://www.ncbi.nlm.nih.gov/pubmed/30700142 30700142 | Intervention/Exposure, Outcome
208 | Lin, SJ, Hwang, SJ, Liu, CY, Lin, HR. The relationship between nutritional status and physical function, admission frequency, length of hospital stay, and mortality in old people living in long-term care facilities. J Nurs Res. 2012. 20:110–21 https://www.ncbi.nlm.nih.gov/pubmed/22592106 22592106 | Study Design, Intervention/Exposure, Health Status
209 | Lingfors, H, Persson, LG. ACM among young men 24-26 years after a lifestyle health dialogue in a Swedish primary care setting: A longitudinal follow-up register study. BMJ Open. 2019. 9:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L626162430 | Intervention/Exposure
210 | Liu, CK, Huang, YC, Lo, YC, Wahlqvist, ML, Lee, MS. Dietary diversity offsets the adverse mortality risk among older indigenous Taiwanese. Asia Pac J Clin Nutr. 2019. 28:593–600 https://www.ncbi.nlm.nih.gov/pubmed/31464406 31464406 | Intervention/Exposure, Country
211 | Liu, CW. Healthy dietary pattern with daily egg consumption might be the true factor associated with decreased risks of cardiovascular diseases and mortality. Heart. 2018. 104:1804 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L624327644 | Study Design
212 | Liu, G, Guasch-Ferre, M, Hu, Y, Li, Y, Hu, FB, Rimm, EB, Manson, JE, Rexrode, KM, Sun, Q. Nut Consumption in Relation to Cardiovascular Disease Incidence and Mortality Among Patients With Diabetes Mellitus. Circ Res. 2019. 124:920–929 https://www.ncbi.nlm.nih.gov/pubmed/30776978 30776978 | Intervention/Exposure
213 | Liu, G, Li, Y, Hu, Y, Zong, G, Li, S, Rimm, EB, Hu, FB, Manson, JE, Rexrode, KM, Shin, HJ, Sun, Q. Influence of Lifestyle on Incident Cardiovascular Disease and Mortality in Patients With Diabetes Mellitus. J Am Coll Cardiol. 2018. 71:2867–2876 https://www.ncbi.nlm.nih.gov/pubmed/29929608 29929608 | Outcome
214 | Liu, ZM, Tse, SLA, Chen, B, Chan, D, Wong, C, Woo, J, Wong, SY. Dietary sugar intake does not pose any risk of bone loss and non-traumatic fracture and is associated with a decrease in ACM among Chinese elderly: Finding from an 11-year longitudinal study of Mr. and Ms. OS Hong Kong. Bone. 2018. 116:154–161 https://www.ncbi.nlm.nih.gov/pubmed/30010084 30010084 | Intervention/Exposure
215 | Lo Buglio, A, Bellanti, F, Capurso, C, Paglia, A, Vendemiale, G. Adherence to Mediterranean Diet, Malnutrition, Length of Stay and Mortality in Elderly Patients Hospitalized in Internal Medicine Wards. Nutrients. 2019. 11:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30959815 | Study Design, Health Status
216 | Loftfield, E, Freedman, ND, Graubard, BI, Guertin, KA, Black, A, Huang, WY, Shebl, FM, Mayne, ST, Sinha, R. Association of Coffee Consumption With Overall and Cause-Specific Mortality in a Large US Prospective Cohort Study. Am J Epidemiol. 2015. 182:1010–22 https://www.ncbi.nlm.nih.gov/pubmed/26614599 26614599 | Intervention/Exposure
217 | Lojko, D, Stelmach-Mardas, M, Suwalska, A. Diet quality and eating patterns in euthymic bipolar patients. Eur Rev Med Pharmacol Sci. 2019. 23:1221–1238 https://www.ncbi.nlm.nih.gov/pubmed/30779092 30779092 | Study Design, Outcome, Health Status
218 | Lonnberg, L, Ekblom-Bak, E, Damberg, M. Improved unhealthy lifestyle habits in patients with high cardiovascular risk: results from a structured lifestyle programme in primary care. Ups J Med Sci. 2019. 124:94–104 https://www.ncbi.nlm.nih.gov/pubmed/31063003 31063003 | Study Design, Intervention/Exposure, Outcome
219 | Loprinzi, PD, Frith, E. Effects of Sedentary Behavior, Physical Activity, Frequency of Protein Consumption, Lower Extremity Strength and Lean Mass on ACM. J Lifestyle Med. 2018. 8:8–15 https://www.ncbi.nlm.nih.gov/pubmed/29581955 29581955 | Intervention/Exposure
220 | Ma, W, Hagan, KA, Heianza, Y, Sun, Q, Rimm, EB, Qi, L. Adult height, dietary patterns, and healthy aging. Am J Clin Nutr. 2017. 106:589–596 https://www.ncbi.nlm.nih.gov/pubmed/28592610 28592610 | Outcome
221 | Malhotra, A, DiNicolantonio, JJ, Capewell, S. It is time to stop counting calories, and time instead to promote dietary changes that substantially and rapidly reduce cardiovascular morbidity and mortality. Open Heart. 2015. 2:e000273 https://www.ncbi.nlm.nih.gov/pubmed/26339496 26339496 | Study Design
222 | Malik, VS, Li, Y, Pan, A, De Koning, L, Schernhammer, E, Willett, WC, Hu, FB. Long-Term Consumption of Sugar-Sweetened and Artificially Sweetened Beverages and Risk of Mortality in US Adults. Circulation. 2019. 139:2113–2125 https://www.ncbi.nlm.nih.gov/pubmed/30882235 30882235 | Intervention/Exposure
223 | Mandalazi, E, Drake, I, WirfÃ¤lt, E, Orho-Melander, M, Sonestedt, E. A high diet quality based on dietary recommendations is not associated with lower incidence of type 2 diabetes in the malmÃ¶ diet and cancer cohort. International Journal of Molecular Sciences. 2016. 17:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L610665168 | Outcome
224 | Mann, J, Morenga, LT, McLean, R, Swinburn, B, Mhurchu, CN, Jackson, R, Kennedy, J, Beaglehole, R. Dietary guidelines on trial: the charges are not evidence based. Lancet. 2016. 388:851–3 https://www.ncbi.nlm.nih.gov/pubmed/27597453 27597453 | Study Design, Intervention/Exposure
225 | Manuel, DG, Perez, R, Sanmartin, C, Taljaard, M, Hennessy, D, Wilson, K, Tanuseputro, P, Manson, H, Bennett, C, Tuna, M, Fisher, S, Rosella, LC. Measuring Burden of Unhealthy Behaviours Using a Multivariable Predictive Approach: Life Expectancy Lost in Canada Attributable to Smoking, Alcohol, Physical Inactivity, and Diet. PLoS Med. 2016. 13:e1002082 https://www.ncbi.nlm.nih.gov/pubmed/27529741 27529741 | Study Design, Intervention/Exposure
226 | Mao, L, Zhang, Y, Wang, W, Zhuang, P, Wu, F, Jiao, J. Plant-sourced and animal-sourced monounsaturated fatty acid intakes in relation to mortality: a prospective nationwide cohort study. Eur J Nutr. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31297602 | Country
227 | MartÃ-nez-GonzÃ¡lez, MA, GarcÃ-a-Arellano, A, Toledo, E, Bes-Rastrollo, M, Bullo, M, Corella, D, Fito, M, Ros, E, Lamuela-RaventÃ³s, RM, Rekondo, J, GÃ³mez-Gracia, E, Fiol, M, Santos-Lozano, JM, Serra-Majem, L, MartÃ-nez, JA, Eguaras, S, SÃ¡ez-Tormo, G, PintÃ³, X, Estruch, R. Obesity indexes and total mortality among elderly subjects at high cardiovascular risk: The PREDIMED study. PLoS ONE. 2014. 9:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L373645014 | Intervention/Exposure
228 | Martin-Calvo, N, Martinez-Gonzalez, MA. Vitamin C Intake is Inversely Associated with Cardiovascular Mortality in a Cohort of Spanish Graduates: the SUN Project. Nutrients. 2017. 9:#pages# https://www.ncbi.nlm.nih.gov/pubmed/28850099 | Intervention/Exposure, Outcome
229 | Martinez-Gomez, D, Guallar-Castillon, P, Higueras-Fresnillo, S, Banegas, JR, Sadarangani, KP, Rodriguez-Artalejo, F. A healthy lifestyle attenuates the effect of polypharmacy on total and cardiovascular mortality: a national prospective cohort study. Sci Rep. 2018. 8:12615 https://www.ncbi.nlm.nih.gov/pubmed/30135569 30135569 | Intervention/Exposure
230 | Martinez-Gonzalez, MA, Salas-Salvado, J, Estruch, R, Corella, D, Fito, M, Ros, E. Benefits of the Mediterranean Diet: insights From the PREDIMED Study. Progress in cardiovascular diseases. 2015. 58:50–60 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01085467/full 25940230 | Study Design, Outcome
231 | Maruyama, K, Iso, H, Date, C, Kikuchi, S, Watanabe, Y, Wada, Y, Inaba, Y, Tamakoshi, A. Dietary patterns and risk of cardiovascular deaths among middle-aged Japanese: JACC Study. Nutr Metab Cardiovasc Dis. 2013. 23:519–27 https://www.ncbi.nlm.nih.gov/pubmed/22410388 22410388 | Outcome
232 | Massimino, FC, Gimeno, SG, Ferreira, SR. ACM among Japanese-Brazilians according to nutritional characteristics. Cad Saude Publica. 2007. 23:2145–56 https://www.ncbi.nlm.nih.gov/pubmed/17700949 17700949 | Intervention/Exposure
233 | May, AM, Struijk, EA, Fransen, HP, Onland-Moret, NC, de Wit, GA, Boer, JM, van der Schouw, YT, Hoekstra, J, Bueno-de-Mesquita, HB, Peeters, PH, Beulens, JW. The impact of a healthy lifestyle on Disability-Adjusted Life Years: a prospective cohort study. BMC Med. 2015. 13:39 https://www.ncbi.nlm.nih.gov/pubmed/25858161 25858161 | Intervention/Exposure, Outcome
234 | McCarthy, WJ, May, F. Evidence for the Full Potential of Daily Food Choices to Minimize Premature Mortality. JAMA Intern Med. 2019. 179:1148–1149 https://www.ncbi.nlm.nih.gov/pubmed/31380948 | Study Design
235 | McCartney, G, Shipley, M, Hart, C, Davey-Smith, G, KivimÃ¤ki, M, Walsh, D, Watt, GC, Batty, GD. Why do males in Scotland die younger than those in England? evidence from three prospective cohort studies. PLoS ONE. 2012. 7:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L365242149 | Intervention/Exposure
236 | Meier, T, Grafe, K, Senn, F, Sur, P, Stangl, GI, Dawczynski, C, Marz, W, Kleber, ME, Lorkowski, S. Cardiovascular mortality attributable to dietary risk factors in 51 countries in the WHO European Region from 1990 to 2016: a systematic analysis of the Global Burden of Disease Study. Eur J Epidemiol. 2019. 34:37–55 https://www.ncbi.nlm.nih.gov/pubmed/30547256 30547256 | Intervention/Exposure, Outcome
237 | Menon, V, Kopple, JD, Wang, X, Beck, GJ, Collins, AJ, Kusek, JW, Greene, T, Levey, AS, Sarnak, MJ. Effect of a very low-protein diet on outcomes: long-term follow-up of the Modification of Diet in Renal Disease (MDRD) Study. Am J Kidney Dis. 2009. 53:208–17 https://www.ncbi.nlm.nih.gov/pubmed/18950911 18950911 | Health Status
238 | Menotti, A, Puddu, PE. Comparison Of Four Dietary Scores As Determinants Of Coronary Heart Disease Mortality. Sci Rep. 2018. 8:15001 https://www.ncbi.nlm.nih.gov/pubmed/30301921 30301921 | Outcome
239 | Menotti, A.,Puddu, P. E.,Maiani, G.,Catasta, G. 2018. Age at death as a useful indicator of healthy aging at population level: a 50-year follow-up of the Italian Rural Areas of the Seven Countries Study Aging Clin Exp Res, 30(8): 901–911. https://www.ncbi.nlm.nih.gov/pubmed/29256065 29256065 | Outcome (data directly overlap with another included article)
240 | Merbach, M, Klaiberg, A, BrÃ¤hler, E. Men and health - An overview of new epidemiological data from Germany. Sozial- und Praventivmedizin. 2001. 46:240–247 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L32842817 11582851 | Language
241 | Merino, J, Guasch-Ferre, M, Martinez-Gonzalez, MA, Corella, D, Estruch, R, Fito, M, Ros, E, Aros, F, Bullo, M, Gomez-Gracia, E, Monino, M, Lapetra, J, Serra-Majem, L, Razquin, C, Buil-Cosiales, P, Sorli, JV, Munoz, MA, Pinto, X, Masana, L, Salas-Salvado, J. Is complying with the recommendations of sodium intake beneficial for health in individuals at high cardiovascular risk? Findings from the PREDIMED study. Am J Clin Nutr. 2015. 101:440–8 https://www.ncbi.nlm.nih.gov/pubmed/25733627 25733627 | Intervention/Exposure
242 | Micha, R, Penalvo, JL, Cudhea, F, Imamura, F, Rehm, CD, Mozaffarian, D. Association Between Dietary Factors and Mortality From Heart Disease, Stroke, and Type 2 Diabetes in the United States. Jama. 2017. 317:912–924 https://www.ncbi.nlm.nih.gov/pubmed/28267855 28267855 | Intervention/Exposure, Outcome
243 | Miller, V, Mente, A, Dehghan, M, Rangarajan, S, Zhang, X, Swaminathan, S, Dagenais, G, Gupta, R, Mohan, V, Lear, S, Bangdiwala, SI, Schutte, AE, Wentzel-Viljoen, E, Avezum, A, Altuntas, Y, Yusoff, K, Ismail, N, Peer, N, Chifamba, J, Diaz, R, Rahman, O, Mohammadifard, N, Lana, F, Zatonska, K, Wielgosz, A, Yusufali, A, Iqbal, R, Lopez-Jaramillo, P, Khatib, R, Rosengren, A, Kutty, VR, Li, W, Liu, J, Liu, X, Yin, L, Teo, K, Anand, S, Yusuf, S. Fruit, vegetable, and legume intake, and cardiovascular disease and deaths in 18 countries (PURE): a prospective cohort study. Lancet. 2017. 390:2037–2049 https://www.ncbi.nlm.nih.gov/pubmed/28864331 28864331 | Intervention/Exposure, Country
244 | Misirli, G, Benetou, V, Lagiou, P, Bamia, C, Trichopoulos, D, Trichopoulou, A. Relation of the traditional Mediterranean diet to cerebrovascular disease in a Mediterranean population. Am J Epidemiol. 2012. 176:1185–92 https://www.ncbi.nlm.nih.gov/pubmed/23186748 23186748 | Outcome
245 | Miyazawa, I, Miura, K, Miyagawa, N, Kondo, K, Kadota, A, Okuda, N, Fujiyoshi, A, Chihara, I, Nakamura, Y, Hozawa, A, ,. Relationship of dietary carbohydrate and fiber intake to risk of cardiovascular disease mortality in Japanese: NIPPON DATA80. Circulation. 2017. 135:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01423697/full | Study design, Publication Status
246 | Miyazawa, I, Miura, K, Miyagawa, N, Kondo, K, Kadota, A, Okuda, N, Fujiyoshi, A, Chihara, I, Nakamura, Y, Hozawa, A, Nakamura, Y, Kita, Y, Yoshita, K, Okamura, T, Okayama, A, Ueshima, H. Relationship between carbohydrate and dietary fibre intake and the risk of cardiovascular disease mortality in Japanese: 24-year follow-up of NIPPON DATA80. Eur J Clin Nutr. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30962516 | Intervention/Exposure, Outcome
247 | Mohammadifard, N, Talaei, M, Sadeghi, M, Oveisegharan, S, Golshahi, J, Esmaillzadeh, A, Sarrafzadegan, N. Dietary patterns and mortality from cardiovascular disease: Isfahan Cohort Study. Eur J Clin Nutr. 2017. 71:252–258 https://www.ncbi.nlm.nih.gov/pubmed/27759064 27759064 | Outcome
248 | Mok, A, Khaw, KT, Luben, R, Wareham, N, Brage, S. Physical activity trajectories and mortality: population based cohort study. Bmj. 2019. 365:l2323 https://www.ncbi.nlm.nih.gov/pubmed/31243014 31243014 | Intervention/Exposure
249 | Moreno, LA, Sarria, A, Popkin, BM. The nutrition transition in Spain: a European Mediterranean country. Eur J Clin Nutr. 2002. 56:992–1003 https://www.ncbi.nlm.nih.gov/pubmed/12373620 12373620 | Study Design, Outcome
250 | Mossavar-Rahmani, Y, Kamensky, V, Manson, JE, Silver, B, Rapp, SR, Haring, B, Beresford, SAA, Snetselaar, L, Wassertheil-Smoller, S. Artificially Sweetened Beverages and Stroke, Coronary Heart Disease, and ACM in the Women’s Health Initiative. Stroke. 2019. 50:555–562 https://www.ncbi.nlm.nih.gov/pubmed/30802187 30802187 | Intervention/Exposure
251 | Mozaffarian, D, Lemaitre, RN, King, IB, Song, X, Huang, H, Sacks, FM, Rimm, EB, Wang, M, Siscovick, DS. Plasma phospholipid long-chain omega-3 fatty acids and total and cause-specific mortality in older adults: a cohort study. Ann Intern Med. 2013. 158:515–25 https://www.ncbi.nlm.nih.gov/pubmed/23546563 23546563 | Intervention/Exposure
252 | Mytton, OT, Forouhi, NG, Scarborough, P, Lentjes, M, Luben, R, Rayner, M, Khaw, KT, Wareham, NJ, Monsivais, P. Association between intake of less-healthy foods defined by the United Kingdom’s nutrient profile model and cardiovascular disease: A population-based cohort study. PLoS Med. 2018. 15:e1002484 https://www.ncbi.nlm.nih.gov/pubmed/29300725 29300725 | Intervention/Exposure, Outcome
253 | Nagai, M, Ohkubo, T, Miura, K, Fujiyoshi, A, Okuda, N, Hayakawa, T, Yoshita, K, Arai, Y, Nakagawa, H, Nakamura, K, Miyagawa, N, Takashima, N, Kadota, A, Murakami, Y, Nakamura, Y, Abbott, RD, Okamura, T, Okayama, A, Ueshima, H. Association of Total Energy Intake with 29-Year Mortality in the Japanese: NIPPON DATA80. J Atheroscler Thromb. 2016. 23:339–54 https://www.ncbi.nlm.nih.gov/pubmed/26460380 26460380 | Intervention/Exposure
254 | Nagata, C, Wada, K, Tamura, T, Konishi, K, Goto, Y. Hot-cold foods in diet and ACM in a Japanese community: the Takayama study. Ann Epidemiol. 2017. 27:194–199.e2 https://www.ncbi.nlm.nih.gov/pubmed/28215585 28215585 | Intervention/Exposure
255 | Nagata, C, Wada, K, Tsuji, M, Kawachi, T, Nakamura, K. Dietary glycaemic index and glycaemic load in relation to all-cause and cause-specific mortality in a Japanese community: the Takayama study. Br J Nutr. 2014. 112:2010–7 https://www.ncbi.nlm.nih.gov/pubmed/25327340 25327340 | Intervention/Exposure
256 | Nakamura, Y, Okamura, T, Kita, Y, Okuda, N, Kadota, A, Miura, K, Okayama, A, Ueshima, H. Re-evaluation of the associations of egg intake with serum total cholesterol and cause-specific and total mortality in Japanese women. Eur J Clin Nutr. 2018. 72:841–847 https://www.ncbi.nlm.nih.gov/pubmed/29288244 29288244 | Intervention/Exposure
257 | Navarro, AM, Martinez-Gonzalez, MA, Gea, A, Grosso, G, Martin-Moreno, JM, Lopez-Garcia, E, Martin-Calvo, N, Toledo, E. Coffee consumption and total mortality in a Mediterranean prospective cohort. Am J Clin Nutr. 2018. 108:1113–1120 https://www.ncbi.nlm.nih.gov/pubmed/30475964 30475964 | Intervention/Exposure
258 | Nohara-Shitama, Y, Adachi, H, Enomoto, M, Fukami, A, Nakamura, S, Kono, S, Morikawa, N, Sakaue, A, Hamamura, H, Toyomasu, K, Fukumoto, Y. Habitual coffee intake reduces ACM by decreasing heart rate. Heart Vessels. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31062117 | Intervention/Exposure
259 | North, SM, Wham, CA, Teh, R, Moyes, SA, Rolleston, A, Kerse, N. High nutrition risk related to dietary intake is associated with an increased risk of hospitalisation and mortality for older Māori: LiLACS NZ. Australian and New Zealand journal of public health. 2018. 42:375–381 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L625611292 29888831 | Intervention/Exposure
260 | North, SM, Wham, CA, Teh, R, Moyes, SA, Rolleston, A, Kerse, N. High nutrition risk related to dietary intake is associated with an increased risk of hospitalisation and mortality for older Maori: LiLACS NZ. Aust N Z J Public Health. 2018. 42:375–381 https://www.ncbi.nlm.nih.gov/pubmed/29888831 29888831 | Study Design, Intervention/Exposure
261 | Nshimyumukiza, L, Lieffers, JRL, Ekwaru, JP, Ohinmaa, A, Veugelers, PJ. Temporal changes in diet quality and the associated economic burden in Canada. PLoS One. 2018. 13:e0206877 https://www.ncbi.nlm.nih.gov/pubmed/30408076 30408076 | Study Design, Outcome
262 | Okada, E, Nakamura, K, Ukawa, S, Sakata, K, Date, C, Iso, H, Tamakoshi, A. Dietary Patterns and Risk of Esophageal Cancer Mortality: The Japan Collaborative Cohort Study. Nutr Cancer. 2016. 68:1001–9 https://www.ncbi.nlm.nih.gov/pubmed/27366932 27366932 | Intervention/Exposure, Outcome
263 | Okada, E, Shirakawa, T, Shivappa, N, Wakai, K, Suzuki, K, Date, C, Iso, H, Hebert, JR, Tamakoshi, A. Dietary Inflammatory Index Is Associated with Risk of All-Cause and Cardiovascular Disease Mortality but Not with Cancer Mortality in Middle-Aged and Older Japanese Adults. J Nutr. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31100121 | Intervention/Exposure
264 | Okuyama, H, Ichikawa, Y, Sun, Y, Hamazaki, T, Lands, WE. Mechanisms by which dietary fats affect coronary heart disease mortality. World Rev Nutr Diet. 2007. 96:119–41 https://www.ncbi.nlm.nih.gov/pubmed/17167284 17167284 | Study Design
265 | Olaya, B, Essau, CA, Moneta, MV, Lara, E, Miret, M, MartÃ-n-MarÃ-a, N, Moreno-Agostino, D, Ayuso-Mateos, JL, Abduljabbar, AS, Haro, JM. Fruit and vegetable consumption and potential moderators associated with ACM in a representative sample of spanish older adults. Nutrients. 2019. 11:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L2002341066 | Intervention/Exposure
266 | Oliveira, ER, Cade, NV, Velten, AP, Silva, GA, Faerstein, E. Comparative study of cardiovascular and cancer mortality of Adventists and non-Adventists from Espirito Santo State, in the period from 2003 to 2009. Rev Bras Epidemiol. 2016. 19:112–21 https://www.ncbi.nlm.nih.gov/pubmed/27167653 27167653 | Study Design, Intervention/Exposure
267 | Osella, AR, Veronese, N, Notarnicola, M, Cisternino, AM, Misciagna, G, Guerra, V, Nitti, A, Campanella, A, Caruso, MG. Potato Consumption Is not Associated with Higher Risk of Mortality: A Longitudinal Study among Southern Italian Older Adults. J Nutr Health Aging. 2018. 22:726–730 https://www.ncbi.nlm.nih.gov/pubmed/29806862 29806862 | Intervention/Exposure
268 | Otsuka, R, Tange, C, Nishita, Y, Tomida, M, Kato, Y, Imai, T, Ando, F, Shimokata, H. Fish and Meat Intake, Serum Eicosapentaenoic Acid and Docosahexaenoic Acid Levels, and Mortality in Community-Dwelling Japanese Older Persons. Int J Environ Res Public Health. 2019. 16:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31117268 | Intervention/Exposure
269 | Otto, MC, Afshin, A, Micha, R, Khatibzadeh, S, Fahimi, S, Singh, G, Danaei, G, Sichieri, R, Monteiro, CA, Louzada, ML, Ezzati, M, Mozaffarian, D. The Impact of Dietary and Metabolic Risk Factors on Cardiovascular Diseases and Type 2 Diabetes Mortality in Brazil. PLoS One. 2016. 11:e0151503 https://www.ncbi.nlm.nih.gov/pubmed/26990765 26990765 | Outcome
270 | Owen, AJ, Magliano, DJ, O’Dea, K, Barr, EL, Shaw, JE. Polyunsaturated fatty acid intake and risk of cardiovascular mortality in a low fish-consuming population: a prospective cohort analysis. Eur J Nutr. 2016. 55:1605–13 https://www.ncbi.nlm.nih.gov/pubmed/26201872 26201872 | Intervention/Exposure
271 | Oyebode, O, Gordon-Dseagu, V, Walker, A, Mindell, JS. Fruit and vegetable consumption and all-cause, cancer and CVD mortality: analysis of Health Survey for England data. J Epidemiol Community Health. 2014. 68:856–62 https://www.ncbi.nlm.nih.gov/pubmed/24687909 24687909 | Intervention/Exposure
272 | Pan, A, Sun, Q, Bernstein, AM, Schulze, MB, Manson, JE, Stampfer, MJ, Willett, WC, Hu, FB. Red meat consumption and mortality: results from 2 prospective cohort studies. Arch Intern Med. 2012. 172:555–63 https://www.ncbi.nlm.nih.gov/pubmed/22412075 22412075 | Intervention/Exposure
273 | Panagiotakos, DB, Georgousopoulou, EN, Pitsavos, C, Chrysohoou, C, Metaxa, V, Georgiopoulos, GA, Kalogeropoulou, K, Tousoulis, D, Stefanadis, C. Ten-year (2002-2012) cardiovascular disease incidence and ACM, in urban Greek population: the ATTICA Study. Int J Cardiol. 2015. 180:178–84 https://www.ncbi.nlm.nih.gov/pubmed/25463360 25463360 | Intervention/Exposure, Outcome
274 | Panagiotakos, DB, Georgousopoulou, EN, Pitsavos, C, Chrysohoou, C, Skoumas, I, Pitaraki, E, Georgiopoulos, GA, Ntertimani, M, Christou, A, Stefanadis, C. Exploring the path of Mediterranean diet on 10-year incidence of cardiovascular disease: the ATTICA study (2002-2012). Nutr Metab Cardiovasc Dis. 2015. 25:327–35 https://www.ncbi.nlm.nih.gov/pubmed/25445882 25445882 | Outcome
275 | Papandreou, C, Becerra-Tomas, N, Bullo, M, Martinez-Gonzalez, MA, Corella, D, Estruch, R, Ros, E, Aros, F, Schroder, H, Fito, M, Serra-Majem, L, Lapetra, J, Fiol, M, Ruiz-Canela, M, Sorli, JV, Salas-Salvado, J. Legume consumption and risk of all-cause, cardiovascular, and cancer mortality in the PREDIMED study. Clin Nutr. 2019. 38:348–356 https://www.ncbi.nlm.nih.gov/pubmed/29352655 29352655 | Intervention/Exposure
276 | Papandreou, C, Tuomilehto, H. Coronary heart disease mortality in relation to dietary, lifestyle and biochemical risk factors in the countries of the Seven Countries Study: a secondary dataset analysis. J Hum Nutr Diet. 2014. 27:168–75 https://www.ncbi.nlm.nih.gov/pubmed/24313566 24313566 | Study Design, Intervention/Exposure
277 | Parikh, A, Lipsitz, SR, Natarajan, S. Association between a DASH-like diet and mortality in adults with hypertension: findings from a population-based follow-up study. Am J Hypertens. 2009. 22:409–16 https://www.ncbi.nlm.nih.gov/pubmed/19197247 19197247 | Intervention/Exposure, Health Status
278 | Park, MK, Paik, HY, Lee, Y. Intake Trends of Red Meat, Alcohol, and Fruits and Vegetables as Cancer-Related Dietary Factors from 1998 to 2009. Osong Public Health Res Perspect. 2016. 7:180–9 https://www.ncbi.nlm.nih.gov/pubmed/27413649 27413649 | Intervention/Exposure
279 | Park, SY, Kang, M, Wilkens, LR, Shvetsov, YB, Harmon, BE, Shivappa, N, Wirth, MD, Hebert, JR, Haiman, CA, Le Marchand, L, Boushey, CJ. The Dietary Inflammatory Index and All-Cause, Cardiovascular Disease, and Cancer Mortality in the Multiethnic Cohort Study. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30513709 | Intervention/Exposure
280 | Park, TS, Jin, HY. Can the incidence and mortality of chronic diseases be explained by dietary patterns?. J Diabetes Investig. 2011. 2:260–1 https://www.ncbi.nlm.nih.gov/pubmed/24843495 | Study Design
281 | Park, YM, Choi, MK, Lee, SS, Shivappa, N, Han, K, Steck, SE, Hebert, JR, Merchant, AT, Sandler, DP. Dietary inflammatory potential and risk of mortality in metabolically healthy and unhealthy phenotypes among overweight and obese adults. Clin Nutr. 2019. 38:682–688 https://www.ncbi.nlm.nih.gov/pubmed/29705061 29705061 | Intervention/Exposure
282 | Pati, S, Singh, RB, Fedacko, J, Vargova, V, Takahashi, T, Tongnuka, M, Juneja, L, De Meester, F. Dietary patterns and causes of death due to cardiovascular diseases and other chronic diseases among urban decedents in North India. World Heart Journal. 2012. 4:123–134 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L369260435 | Outcome, Country
283 | Paxton, RJ, Jones, LA, Chang, S, Hernandez, M, Hajek, RA, Flatt, SW, Natarajan, L, Pierce, JP. Was race a factor in the outcomes of the Women’s Health Eating and Living Study?. Cancer. 2011. 117:3805–13 https://www.ncbi.nlm.nih.gov/pubmed/21319157 21319157 | Health Status
284 | Poledne, R, Skodova, Z. Changes in nutrition, cholesterol concentration, and cardiovascular disease mortality in the Czech population in the past decade. Nutrition. 2000. 16:785–6 https://www.ncbi.nlm.nih.gov/pubmed/10978865 10978865 | Study Design, Intervention/Exposure, Outcome
285 | Ponzo, V, Gentile, L, Gambino, R, Rosato, R, Cioffi, I, Pellegrini, N, Benso, A, Broglio, F, Cassader, M, Bo, S. Incidence of diabetes mellitus, cardiovascular outcomes and mortality after a 12-month lifestyle intervention: a 9-year follow-up. Diabetes & metabolism. 2018. 44:449–451 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01651501/full 29773350 | Study Design
286 | Pounis, G, Costanzo, S, Bonaccio, M, Di Castelnuovo, A, de Curtis, A, Ruggiero, E, Persichillo, M, Cerletti, C, Donati, MB, de Gaetano, G, Iacoviello, L. Reduced mortality risk by a polyphenol-rich diet: An analysis from the Moli-sani study. Nutrition. 2018. 48:87–95 https://www.ncbi.nlm.nih.gov/pubmed/29469027 29469027 | Intervention/Exposure
287 | Poursafar, Z, Joukar, F, Hasavari, F, Atrkar Roushan, Z. The Associations between Meat Group Consumption and Acute Myocardial Infarction Risks in an Iranian Population: a Case-Control Study. Clin Nutr Res. 2019. 8:159–168 https://www.ncbi.nlm.nih.gov/pubmed/31089469 31089469 | Study Design, Outcome
288 | Praagman, J, Dalmeijer, GW, van der Schouw, YT, Soedamah-Muthu, SS, Monique Verschuren, WM, Bas Bueno-de-Mesquita, H, Geleijnse, JM, Beulens, JW. The relationship between fermented food intake and mortality risk in the European Prospective Investigation into Cancer and Nutrition-Netherlands cohort. Br J Nutr. 2015. 113:498–506 https://www.ncbi.nlm.nih.gov/pubmed/25599866 25599866 | Intervention/Exposure
289 | Prentice, RL, Aragaki, AK, Van Horn, L, Thomson, CA, Beresford, SA, Robinson, J, Snetselaar, L, Anderson, GL, Manson, JE, Allison, MA, Rossouw, JE, Howard, BV. Low-fat dietary pattern and cardiovascular disease: results from the Women’s Health Initiative randomized controlled trial. Am J Clin Nutr. 2017. 106:35–43 https://www.ncbi.nlm.nih.gov/pubmed/28515068 28515068 | Intervention/Exposure, Outcome
290 | Puaschitz, NG, Assmus, J, Strand, E, Karlsson, T, Vinknes, KJ, Lysne, V, Drevon, CA, Tell, GS, Dierkes, J, Nygard, O. Adherence to the Healthy Nordic Food Index and the incidence of acute myocardial infarction and mortality among patients with stable angina pectoris. J Hum Nutr Diet. 2019. 32:86–97 https://www.ncbi.nlm.nih.gov/pubmed/30091209 30091209 | Health Status
291 | Puaschitz, NG, Strand, E, Norekval, TM, Dierkes, J, Dahl, L, Svingen, GF, Assmus, J, Schartum-Hansen, H, Oyen, J, Pedersen, EK, Drevon, CA, Tell, GS, Nygard, O. Dietary intake of saturated fat is not associated with risk of coronary events or mortality in patients with established coronary artery disease. J Nutr. 2015. 145:299–305 https://www.ncbi.nlm.nih.gov/pubmed/25644351 25644351 | Intervention/Exposure, Health Status
292 | Ramage-Morin, PL, Gilmour, H, Rotermann, M. Nutritional risk, hospitalization and mortality among community-dwelling Canadians aged 65 or older. Health Rep. 2017. 28:17–27 https://www.ncbi.nlm.nih.gov/pubmed/28930364 28930364 | Intervention/Exposure
293 | Ramne, S, Alves Dias, J, Gonzalez-Padilla, E, Olsson, K, Lindahl, B, Engstrom, G, Ericson, U, Johansson, I, Sonestedt, E. Association between added sugar intake and mortality is nonlinear and dependent on sugar source in 2 Swedish population-based prospective cohorts. Am J Clin Nutr. 2019. 109:411–423 https://www.ncbi.nlm.nih.gov/pubmed/30590448 30590448 | Intervention/Exposure
294 | Rathod, AD, Bharadwaj, AS, Badheka, AO, Kizilbash, M, Afonso, L. Healthy Eating Index and mortality in a nationally representative elderly cohort. Arch Intern Med. 2012. 172:275–7 https://www.ncbi.nlm.nih.gov/pubmed/22332163 22332163 | Study Design
295 | Ravichandran, M, Grandl, G, Ristow, M. Dietary Carbohydrates Impair Healthspan and Promote Mortality. Cell Metab. 2017. 26:585–587 https://www.ncbi.nlm.nih.gov/pubmed/28978421 28978421 | Study Design
296 | Rebello, SA, Koh, H, Chen, C, Naidoo, N, Odegaard, AO, Koh, WP, Butler, LM, Yuan, JM, van Dam, RM. Amount, type, and sources of carbohydrates in relation to ischemic heart disease mortality in a Chinese population: a prospective cohort study. Am J Clin Nutr. 2014. 100:53–64 https://www.ncbi.nlm.nih.gov/pubmed/24787492 24787492 | Intervention/Exposure, Outcome
297 | Redfern, RC, DeWitte, SN, Beaumont, J, Millard, AR, Hamlin, C. A new method for investigating the relationship between diet and mortality: hazard analysis using dietary isotopes. Ann Hum Biol. 2019. #volume#:1–10 https://www.ncbi.nlm.nih.gov/pubmed/31475587 30856008 | Study Design
298 | Reedy, J, Lerman, JL, Krebs-Smith, SM, Kirkpatrick, SI, Pannucci, TE, Wilson, MM, Subar, AF, Kahle, LL, Tooze, JA. Evaluation of the Healthy Eating Index-2015. J Acad Nutr Diet. 2018. 118:1622–1633 https://www.ncbi.nlm.nih.gov/pubmed/30146073 30146073 | Outcome
299 | Rehberg, J, Stipcic, A, Coric, T, Kolcic, I, Polasek, O. Mortality patterns in Southern Adriatic islands of Croatia: a registry-based study. Croat Med J. 2018. 59:118–123 https://www.ncbi.nlm.nih.gov/pubmed/29972734 29972734 | Intervention/Exposure
300 | Rezende, LF, Azeredo, CM, Canella, DS, Luiz Odo, C, Levy, RB, Eluf-Neto, J. Coronary heart disease mortality, cardiovascular disease mortality and ACM attributable to dietary intake over 20years in Brazil. Int J Cardiol. 2016. 217:64–8 https://www.ncbi.nlm.nih.gov/pubmed/27179210 27179210 | Study Design, Intervention/Exposure
301 | Ricci, C, Baumgartner, J, Zec, M, Kruger, HS, Smuts, CM. Type of dietary fat intakes in relation to all-cause and cause-specific mortality in US adults: an iso-energetic substitution analysis from the American National Health and Nutrition Examination Survey linked to the US mortality registry. Br J Nutr. 2018. 119:456–463 https://www.ncbi.nlm.nih.gov/pubmed/29498349 29498349 | Intervention/Exposure
302 | Rodrigues, SSP, Trichopoulou, A, De Almeida, MDV. Household diet quality in relation to mortality in Portuguese regions: An ecological study. Journal of Public Health. 2008. 16:43–51 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L351018329 | Study Design
303 | Ross, SM. Cardiovascular disease mortality: the deleterious effects of excess dietary sugar intake. Holist Nurs Pract. 2015. 29:53–7 https://www.ncbi.nlm.nih.gov/pubmed/25470481 25470481 | Study Design, Outcome
304 | Rowbotham, J, Clayton, P. An unsuitable and degraded diet? Part three: Victorian consumption patterns and their health benefits. J R Soc Med. 2008. 101:454–62 https://www.ncbi.nlm.nih.gov/pubmed/18779247 18779247 | Study Design, Intervention/Exposure
305 | Russell, J, Flood, V, Rochtchina, E, Gopinath, B, Allman-Farinelli, M, Bauman, A, Mitchell, P. Adherence to dietary guidelines and 15-year risk of ACM. Br J Nutr. 2013. 109:547–55 https://www.ncbi.nlm.nih.gov/pubmed/22571690 22571690 | Intervention/Exposure, Health Status
306 | Saglimbene, VM, Wong, G, Craig, JC, Ruospo, M, Palmer, SC, Campbell, K, Garcia-Larsen, V, Natale, P, Teixeira-Pinto, A, Carrero, JJ, Stenvinkel, P, Gargano, L, Murgo, AM, Johnson, DW, Tonelli, M, Gelfman, R, Celia, E, Ecder, T, Bernat, AG, Del Castillo, D, Timofte, D, Torok, M, Bednarek-Skublewska, A, Dulawa, J, Stroumza, P, Hoischen, S, Hansis, M, Fabricius, E, Felaco, P, Wollheim, C, Hegbrant, J, Strippoli, GFM. The Association of Mediterranean and DASH Diets with Mortality in Adults on Hemodialysis: The DIET-HD Multinational Cohort Study. J Am Soc Nephrol. 2018. 29:1741–1751 https://www.ncbi.nlm.nih.gov/pubmed/29695436 29695436 | Health Status
307 | Saha, S, Nordstrom, J, Gerdtham, UG, Mattisson, I, Nilsson, PM, Scarborough, P. Prevention of Cardiovascular Disease and Cancer Mortality by Achieving Healthy Dietary Goals for the Swedish Population: A Macro-Simulation Modelling Study. Int J Environ Res Public Health. 2019. 16:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30870975 | Intervention/Exposure, Outcome
308 | Saha, S, Nordstrom, J, Mattisson, I, Nilsson, PM, Gerdtham, UG. Modelling the Effect of Compliance with Nordic Nutrition Recommendations on Cardiovascular Disease and Cancer Mortality in the Nordic Countries. Nutrients. 2019. 11:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31242671 | Study Design, Intervention/Exposure
309 | Sala-Vila, A, Guasch-FerrÃ©, M, Hu, FB, SÃ¡nchez-Tainta, A, BullÃ³, M, Serra-Mir, M, LÃ³pez-Sabater, C, SorlÃ-, JV, ArÃ³s, F, Fiol, M, ,. Dietary Î±-Linolenic Acid, Marine Ï‰-3 Fatty Acids, and Mortality in a Population With High Fish Consumption: findings From the PREvenciÃ³n con DIeta MEDiterrÃ¡nea (PREDIMED) Study. Journal of the american heart association. 2016. 5:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01200327/full | Intervention/Exposure
310 | Sandoval-Insausti, H, Blanco-Rojo, R, Graciani, A, Lopez-Garcia, E, Moreno-Franco, B, Laclaustra, M, Donat-Vargas, C, Ordovas, JM, Rodriguez-Artalejo, F, Guallar-Castillon, P. Ultra-processed Food Consumption and Incident Frailty: A prospective Cohort Study of Older Adults. J Gerontol A Biol Sci Med Sci. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31132092 | Intervention/Exposure, Outcome
311 | Sangita, S, Vik, SA, Pakseresht, M, Kolonel, LN. Adherence to recommendations for fruit and vegetable intake, ethnicity and ischemic heart disease mortality. Nutr Metab Cardiovasc Dis. 2013. 23:1247–54 https://www.ncbi.nlm.nih.gov/pubmed/23725771 23725771 | Outcome
312 | Sauer, AC, Goates, S, Malone, A, Mogensen, KM, Gewirtz, G, Sulz, I, Moick, S, Laviano, A, Hiesmayr, M. Prevalence of Malnutrition Risk and the Impact of Nutrition Risk on Hospital Outcomes: Results From nutritionDay in the U.S. JPEN J Parenter Enteral Nutr. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30666659 | Study Design, Health Status
313 | Scarborough, P, Allender, S, Rayner, M, Goldacre, M. An index of unhealthy lifestyle is associated with coronary heart disease mortality rates for small areas in England after adjustment for deprivation. Health Place. 2011. 17:691–5 https://www.ncbi.nlm.nih.gov/pubmed/21216177 21216177 | Study Design, Outcome
314 | Scarborough, P, Morgan, RD, Webster, P, Rayner, M. Differences in coronary heart disease, stroke and cancer mortality rates between England, Wales, Scotland and Northern Ireland: the role of diet and nutrition. BMJ Open. 2011. 1:e000263 https://www.ncbi.nlm.nih.gov/pubmed/22080528 | Intervention/Exposure, Outcome
315 | Scarborough, P, Nnoaham, KE, Clarke, D, Capewell, S, Rayner, M. Modelling the impact of a healthy diet on cardiovascular disease and cancer mortality. J Epidemiol Community Health. 2012. 66:420–6 https://www.ncbi.nlm.nih.gov/pubmed/21172796 21172796 | Study Design, Intervention/Exposure
316 | Schooling, CM, Ho, SY, Leung, GM, Thomas, GN, McGhee, SM, Mak, KH, Lam, TH. Diet synergies and mortality--a population-based case-control study of 32,462 Hong Kong Chinese older adults. Int J Epidemiol. 2006. 35:418–26 https://www.ncbi.nlm.nih.gov/pubmed/16394118 16394118 | Study Design, Country
317 | Schroder, H, Cardenas-Fuentes, G, Martinez-Gonzalez, MA, Corella, D, Vioque, J, Romaguera, D, Alfredo Martinez, J, Tinahones, FJ, Miranda, JL, Estruch, R, Bueno-Cavanillas, A, Aros, F, Marcos, A, Tur, JA, Warnberg, J, Serra-Majem, L, Martin, V, Vazquez, C, Lapetra, J, Pinto, X, Vidal, J, Daimiel, L, Gaforio, JJ, Matia-Martin, P, Ros, E, Castaner, O, Lassale, C, Ruiz-Canela, M, Asensio, EM, Basora, J, Torres-Collado, L, Garcia-Rios, A, Abete, I, Toledo, E, Buil-Cosiales, P, Bullo, M, Goday, A, Fito, M, Salas-Salvado, J. Effectiveness of the physical activity intervention program in the PREDIMED-Plus study: a randomized controlled trial. Int J Behav Nutr Phys Act. 2018. 15:110 https://www.ncbi.nlm.nih.gov/pubmed/30424822 30424822 | Intervention/Exposure, Outcome
318 | Schwenke, DC. Dietary patterns to reduce mortality and promote independent functioning. Curr Opin Lipidol. 2019. 30:256–257 https://www.ncbi.nlm.nih.gov/pubmed/31045607 31045607 | Study Design
319 | Schwenke, DC. Optimizing dietary patterns to decrease premature mortality. Curr Opin Lipidol. 2017. 28:381–382 https://www.ncbi.nlm.nih.gov/pubmed/28700379 28700379 | Study Design
320 | Seah, JY, Ong, CN, Koh, WP, Yuan, JM, van Dam, RM. A Dietary Pattern Derived from Reduced Rank Regression and Fatty Acid Biomarkers Is Associated with Lower Risk of Type 2 Diabetes and Coronary Artery Disease in Chinese Adults. J Nutr. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31386157 | Intervention/Exposure, Outcome
321 | Segovia-Siapco, G, SabatÃ©, J. Health and sustainability outcomes of vegetarian dietary patterns: a revisit of the EPIC-Oxford and the Adventist Health Study-2 cohorts. European Journal of Clinical Nutrition. 2018. #volume#:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L625313508 | Study Design
322 | Seguro, F, Taraszkiewicz, D, Bongard, V, Berard, E, Bouisset, F, Ruidavets, JB, Ferrieres, J. Ignorance of cardiovascular preventive measures is associated with all-cause and cardiovascular mortality in the French general population. Arch Cardiovasc Dis. 2016. 109:486–93 https://www.ncbi.nlm.nih.gov/pubmed/27342804 27342804 | Intervention/Exposure
323 | Seidelmann, S. B.,Claggett, B.,Cheng, S.,Henglin, M.,Shah, A.,Steffen, L. M.,Folsom, A. R.,Rimm, E. B.,Willett, W. C.,Solomon, S. D. 2018. Dietary carbohydrate intake and mortality: a prospective cohort study and meta-analysis The Lancet Public Health, 3(9): e419–e428. http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L2001133282 30122560 | Intervention/Exposure: did not describe the macronutrient distribution of the diet for the categories analyzed
324 | Shea, MK, Nicklas, BJ, Houston, DK, Miller, ME, Davis, CC, Kitzman, DW, Espeland, MA, Appel, LJ, Kritchevsky, SB. The effect of intentional weight loss on ACM in older adults: Results of a randomized controlled weight-loss trial. American Journal of Clinical Nutrition. 2011. 94:839–846 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L362402891 | Intervention/Exposure
325 | Shi, Z, Zhang, T, Byles, J, Martin, S, Avery, JC, Taylor, AW. Food Habits, Lifestyle Factors and Mortality among Oldest Old Chinese: The Chinese Longitudinal Healthy Longevity Survey (CLHLS). Nutrients. 2015. 7:7562–79 https://www.ncbi.nlm.nih.gov/pubmed/26371039 26371039 | Intervention/Exposure
326 | Shi, Z, Zhen, S, Zimmet, PZ, Zhou, Y, Zhou, Y, Magliano, DJ, Taylor, AW. Association of impaired fasting glucose, diabetes and dietary patterns with mortality: a 10-year follow-up cohort in Eastern China. Acta Diabetol. 2016. 53:799–806 https://www.ncbi.nlm.nih.gov/pubmed/27311686 27311686 | Country
327 | Shikany, JM, Safford, MM, Bryan, J, Newby, PK, Richman, JS, Durant, RW, Brown, TM, Judd, SE. Dietary Patterns and Mediterranean Diet Score and Hazard of Recurrent Coronary Heart Disease Events and ACM in the REGARDS Study. J Am Heart Assoc. 2018. 7:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30005552 | Health Status
328 | Shimazu, T, Kuriyama, S, Hozawa, A, Ohmori, K, Sato, Y, Nakaya, N, Nishino, Y, Tsubono, Y, Tsuji, I. Dietary patterns and cardiovascular disease mortality in Japan: a prospective cohort study. Int J Epidemiol. 2007. 36:600–9 https://www.ncbi.nlm.nih.gov/pubmed/17317693 17317693 | Outcome
329 | Shirai, K. Ideal body mass index determined by mortality in Europe, and adequate high protein and low carbohydrate diet to maintain bodyweight. J Diabetes Investig. 2011. 2:421–2 https://www.ncbi.nlm.nih.gov/pubmed/24843524 | Study Design
330 | Shivappa, N, Blair, CK, Prizment, AE, Jacobs, DR, Jr, Steck, SE, Hebert, JR. Association between inflammatory potential of diet and mortality in the Iowa Women’s Health study. Eur J Nutr. 2016. 55:1491–502 https://www.ncbi.nlm.nih.gov/pubmed/26130324 26130324 | Intervention/Exposure
331 | Shivappa, N, Harris, H, Wolk, A, Hebert, JR. Association between inflammatory potential of diet and mortality among women in the Swedish Mammography Cohort. Eur J Nutr. 2016. 55:1891–900 https://www.ncbi.nlm.nih.gov/pubmed/26227485 26227485 | Intervention/Exposure
332 | Shivappa, N, Steck, SE, Hussey, JR, Ma, Y, Hebert, JR. Inflammatory potential of diet and all-cause, cardiovascular, and cancer mortality in National Health and Nutrition Examination Survey III Study. Eur J Nutr. 2017. 56:683–692 https://www.ncbi.nlm.nih.gov/pubmed/26644215 26644215 | Intervention/Exposure
333 | Singh-Manoux, A, Fayosse, A, Sabia, S, Tabak, A, Shipley, M, Dugravot, A, Kivimaki, M. Clinical, socioeconomic, and behavioural factors at age 50 years and risk of cardiometabolic multimorbidity and mortality: A cohort study. PLoS Med. 2018. 15:e1002571 https://www.ncbi.nlm.nih.gov/pubmed/29782486 29782486 | Intervention/Exposure
334 | Sluik, D, Boeing, H, Li, K, Kaaks, R, Johnsen, NF, Tjonneland, A, Arriola, L, Barricarte, A, Masala, G, Grioni, S, Tumino, R, Ricceri, F, Mattiello, A, Spijkerman, AM, van der, Dl A, Sluijs, I, Franks, PW, Nilsson, PM, Orho-Melander, M, Fharm, E, Rolandsson, O, Riboli, E, Romaguera, D, Weiderpass, E, Sanchez-Cantalejo, E, Nothlings, U. Lifestyle factors and mortality risk in individuals with diabetes mellitus: are the associations different from those in individuals without diabetes?. Diabetologia. 2014. 57:63–72 https://www.ncbi.nlm.nih.gov/pubmed/24132780 24132780 | Intervention/Exposure, Health Status
335 | Smigielski, J, Bielecki, W, Drygas, W. Health and life style-related determinants of survival rate in the male residents of the city of Łódź. International journal of occupational medicine and environmental health. 2013. 26:337–348 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L563064394 24018994 | Intervention/Exposure
336 | Smigielski, J, Jegier, A, Hanke, W, Bielecki, W, Drygas, W. The effect of selected lifestyle factors and diet on mortality of men with documented physical fitness in the city of Łódź. International journal of occupational medicine and environmental health. 2013. 26:535–544 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L603534972 24052150 | Intervention/Exposure
337 | Smigielski, J, Jegier, A, Hanke, W, Bielecki, W, Drygas, W. The effect of selected lifestyle factors and diet on mortality of men with documented physical fitness in the city of Lodz. Int J Occup Med Environ Health. 2013. 26:535–44 https://www.ncbi.nlm.nih.gov/pubmed/24052150 24052150 | Intervention/Exposure
338 | Smyth, A, Griffin, M, Yusuf, S, Mann, JF, Reddan, D, Canavan, M, Newell, J, O’Donnell, M. Diet and Major Renal Outcomes: A Prospective Cohort Study. The NIH-AARP Diet and Health Study. J Ren Nutr. 2016. 26:288–98 https://www.ncbi.nlm.nih.gov/pubmed/26975776 26975776 | Outcome
339 | Sofi, F, Abbate, R, Gensini, GF, Casini, A, Trichopoulou, A, Bamia, C. Identification of change-points in the relationship between food groups in the Mediterranean diet and overall mortality: an ‘a posteriori’ approach. Eur J Nutr. 2012. 51:167–72 https://www.ncbi.nlm.nih.gov/pubmed/21541730 21541730 | Intervention/Exposure
340 | Solfrizzi, V, D’Introno, A, Colacicco, AM, Capurso, C, Palasciano, R, Capurso, S, Torres, F, Capurso, A, Panza, F. Unsaturated fatty acids intake and all-causes mortality: a 8.5-year follow-up of the Italian Longitudinal Study on Aging. Exp Gerontol. 2005. 40:335–43 https://www.ncbi.nlm.nih.gov/pubmed/15820615 15820615 | Intervention/Exposure
341 | Sonestedt, E, Gullberg, B, Ericson, U, Wirfalt, E, Hedblad, B, Orho-Melander, M. Association between fat intake, physical activity and mortality depending on genetic variation in FTO. Int J Obes (Lond). 2011. 35:1041–9 https://www.ncbi.nlm.nih.gov/pubmed/21179003 21179003 | Intervention/Exposure
342 | Song, M, Alexander, CM, Mavros, P, Lopez, VA, Malik, S, Phatak, HM, Wong, ND. Use of the UKPDS Outcomes Model to predict ACM in U.S. adults with type 2 diabetes mellitus: comparison of predicted versus observed mortality. Diabetes Res Clin Pract. 2011. 91:121–6 https://www.ncbi.nlm.nih.gov/pubmed/21074286 21074286 | Study Design, Intervention/Exposure, Health Status
343 | Song, M, Wu, K, Meyerhardt, JA, Yilmaz, O, Wang, M, Ogino, S, Fuchs, CS, Giovannucci, EL, Chan, AT. Low-Carbohydrate Diet Score and Macronutrient Intake in Relation to Survival After Colorectal Cancer Diagnosis. JNCI Cancer Spectr. 2018. 2:pky077 https://www.ncbi.nlm.nih.gov/pubmed/30734025 30734025 | Outcome, Health Status
344 | Srour, B, Touvier, M, Julia, C. Evidence for the Full Potential of Daily Food Choices to Minimize Premature Mortality-Reply. JAMA Intern Med. 2019. 179:1149–1150 https://www.ncbi.nlm.nih.gov/pubmed/31380952 31380952 | Study Design
345 | Steffen, LM, Jacobs, DR, Jr, Stevens, J, Shahar, E, Carithers, T, Folsom, AR. Associations of whole-grain, refined-grain, and fruit and vegetable consumption with risks of ACM and incident coronary artery disease and ischemic stroke: the Atherosclerosis Risk in Communities (ARIC) Study. Am J Clin Nutr. 2003. 78:383–90 https://www.ncbi.nlm.nih.gov/pubmed/12936919 12936919 | Intervention/Exposure
346 | Stefler, D, Pikhart, H, Jankovic, N, Kubinova, R, Pajak, A, Malyutina, S, Simonova, G, Feskens, EJM, Peasey, A, Bobak, M. Healthy diet indicator and mortality in Eastern European populations: prospective evidence from the HAPIEE cohort. Eur J Clin Nutr. 2014. 68:1346–1352 https://www.ncbi.nlm.nih.gov/pubmed/25028084 25028084 | Intervention/Exposure
347 | Stewart, D, Han, L, Doran, T, McCambridge, J. Alcohol consumption and ACM: an analysis of general practice database records for patients with long-term conditions. Journal of epidemiology and community health. 2017. 71:729–735 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L622153652 28679541 | Intervention/Exposure
348 | Stewart, RA, Wallentin, L, Benatar, J, Danchin, N, Hagstrom, E, Held, C, Husted, S, Lonn, E, Stebbins, A, Chiswell, K, Vedin, O, Watson, D, White, HD. Dietary patterns and the risk of major adverse cardiovascular events in a global study of high-risk patients with stable coronary heart disease. Eur Heart J. 2016. 37:1993–2001 https://www.ncbi.nlm.nih.gov/pubmed/27109584 27109584 | Health Status
349 | Streicher, M, Themessl-Huber, M, Schindler, K, Sieber, CC, Hiesmayr, M, Volkert, D. nutritionDay in Nursing Homes-The Association of Nutritional Intake and Nutritional Interventions With 6-Month Mortality in Malnourished Residents. J Am Med Dir Assoc. 2017. 18:162–168 https://www.ncbi.nlm.nih.gov/pubmed/27742584 27742584 | Study Design, Intervention/Exposure
350 | Streppel, MT, Sluik, D, van Yperen, JF, Geelen, A, Hofman, A, Franco, OH, Witteman, JC, Feskens, EJ. Nutrient-rich foods, cardiovascular diseases and ACM: the Rotterdam study. Eur J Clin Nutr. 2014. 68:741–7 https://www.ncbi.nlm.nih.gov/pubmed/24642783 24642783 | Intervention/Exposure
351 | Stringhini, S, Dugravot, A, Shipley, M, Goldberg, M, Zins, M, Kivimaki, M, Marmot, M, Sabia, S, Singh-Manoux, A. Health behaviours, socioeconomic status, and mortality: further analyses of the British Whitehall II and the French GAZEL prospective cohorts. PLoS Med. 2011. 8:e1000419 https://www.ncbi.nlm.nih.gov/pubmed/21364974 21364974 | Study Design, Intervention/Exposure
352 | Sun, Y, Liu, B, Snetselaar, LG, Robinson, JG, Wallace, RB, Peterson, LL, Bao, W. Association of fried food consumption with all cause, cardiovascular, and cancer mortality: prospective cohort study. Bmj. 2019. 364:k5420 https://www.ncbi.nlm.nih.gov/pubmed/30674467 30674467 | Intervention/Exposure
353 | Takata, Y, Zhang, X, Li, H, Gao, YT, Yang, G, Gao, J, Cai, H, Xiang, YB, Zheng, W, Shu, XO. Fish intake and risks of total and cause-specific mortality in 2 population-based cohort studies of 134,296 men and women. Am J Epidemiol. 2013. 178:46–57 https://www.ncbi.nlm.nih.gov/pubmed/23788668 23788668 | Intervention/Exposure
354 | Talaei, M, Koh, WP, Yuan, JM, van Dam, RM. DASH Dietary Pattern, Mediation by Mineral Intakes, and the Risk of Coronary Artery Disease and Stroke Mortality. J Am Heart Assoc. 2019. 8:e011054 https://www.ncbi.nlm.nih.gov/pubmed/30806152 30806152 | Outcome
355 | Talegawkar, SA, Bandinelli, S, Bandeen-Roche, K, Chen, P, Milaneschi, Y, Tanaka, T, Semba, RD, Guralnik, JM, Ferrucci, L. A higher adherence to a Mediterranean-style diet is inversely associated with the development of frailty in community-dwelling elderly men and women. J Nutr. 2012. 142:2161–6 https://www.ncbi.nlm.nih.gov/pubmed/23096005 23096005 | Outcome
356 | Tang, Z, Zhou, T, Luo, Y, Xie, C, Huo, D, Tao, L, Pan, L, Sun, F, Zhu, H, Yang, X, Wang, W, Yan, A, Li, X, Guo, X. Risk factors for cerebrovascular disease mortality among the elderly in Beijing: A competing risk analysis. PLoS ONE. 2014. 9:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L372510278 | Intervention/Exposure, Outcome
357 | Tektonidis, TG, Akesson, A, Gigante, B, Wolk, A, Larsson, SC. Adherence to a Mediterranean diet is associated with reduced risk of heart failure in men. Eur J Heart Fail. 2016. 18:253–9 https://www.ncbi.nlm.nih.gov/pubmed/26781788 26781788 | Outcome
358 | Tharrey, M, Mariotti, F, Mashchak, A, Barbillon, P, Delattre, M, Fraser, GE. Patterns of plant and animal protein intake are strongly associated with cardiovascular mortality: the Adventist Health Study-2 cohort. Int J Epidemiol. 2018. 47:1603–1612 https://www.ncbi.nlm.nih.gov/pubmed/29618018 29618018 | Outcome
359 | Tharrey, M, Mariotti, F, Mashchak, A, Barbillon, P, Delattre, M, Huneau, JF, Fraser, GE. Patterns of amino acids intake are strongly associated with cardiovascular mortality, independently of the sources of protein. Int J Epidemiol. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31562518 | Intervention/Exposure, Outcome
360 | Thomas, GN, Wang, MP, Ho, SY, Mak, KH, Cheng, KK, Lam, TH. Adverse lifestyle leads to an annual excess of 2 million deaths in China. PLoS ONE. 2014. 9:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L372616936 | Intervention/Exposure
361 | Thomson, CA, McCullough, ML, Wertheim, BC, Chlebowski, RT, Martinez, ME, Stefanick, ML, Rohan, TE, Manson, JE, Tindle, HA, Ockene, J, Vitolins, MZ, Wactawski-Wende, J, Sarto, GE, Lane, DS, Neuhouser, ML. Nutrition and physical activity cancer prevention guidelines, cancer risk, and mortality in the women’s health initiative. Cancer Prev Res (Phila). 2014. 7:42–53 https://www.ncbi.nlm.nih.gov/pubmed/24403289 24403289 | Intervention/Exposure
362 | Thomson, CA, Van Horn, L, Caan, BJ, Aragaki, AK, Chlebowski, RT, Manson, JE, Rohan, TE, Tinker, LF, Kuller, LH, Hou, L, Lane, DS, Johnson, KC, Vitolins, MZ, Prentice, RL. Cancer incidence and mortality during the intervention and postintervention periods of the Women’s Health Initiative dietary modification trial. Cancer Epidemiol Biomarkers Prev. 2014. 23:2924–35 https://www.ncbi.nlm.nih.gov/pubmed/25258014 25258014 | Intervention/Exposure
363 | Tognon, G, Rothenberg, E, Petrolo, M, Sundh, V, Lissner, L. Dairy product intake and mortality in a cohort of 70-year-old Swedes: a contribution to the Nordic diet discussion. Eur J Nutr. 2018. 57:2869–2876 https://www.ncbi.nlm.nih.gov/pubmed/29080977 29080977 | Intervention/Exposure
364 | Tomata, Y, Shivappa, N, Zhang, S, Nurrika, D, Tanji, F, Sugawara, Y, Hebert, JR, Tsuji, I. Dietary Inflammatory Index and Disability-Free Survival in Community-Dwelling Older Adults. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30513971 | Outcome
365 | Torfadottir, JE, Valdimarsdottir, UA, Mucci, LA, Kasperzyk, JL, Fall, K, Tryggvadottir, L, Aspelund, T, Olafsson, O, Harris, TB, Jonsson, E, Tulinius, H, Gudnason, V, Adami, HO, Stampfer, M, Steingrimsdottir, L. Consumption of fish products across the lifespan and prostate cancer risk. PLoS One. 2013. 8:e59799 https://www.ncbi.nlm.nih.gov/pubmed/23613715 23613715 | Intervention/Exposure, Outcome
366 | Torres-Collado, L, Garcia-de-la-Hera, M, Navarrete-Munoz, EM, Notario-Barandiaran, L, Gonzalez-Palacios, S, Zurriaga, O, Melchor, I, Vioque, J. Coffee consumption and mortality from all causes of death, cardiovascular disease and cancer in an elderly Spanish population. Eur J Nutr. 2018. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30066178 | Intervention/Exposure
367 | Tresserra-Rimbau, A, Rimm, EB, Medina-Remon, A, Martinez-Gonzalez, MA, Lopez-Sabater, MC, Covas, MI, Corella, D, Salas-Salvado, J, Gomez-Gracia, E, Lapetra, J, Aros, F, Fiol, M, Ros, E, Serra-Majem, L, Pinto, X, Munoz, MA, Gea, A, Ruiz-Gutierrez, V, Estruch, R, Lamuela-Raventos, RM. Polyphenol intake and mortality risk: a re-analysis of the PREDIMED trial. BMC Med. 2014. 12:77 https://www.ncbi.nlm.nih.gov/pubmed/24886552 24886552 | Intervention/Exposure
368 | Trichopoulos, D, Lagiou, P. Mediterranean diet and overall mortality differences in the European Union. Public Health Nutr. 2004. 7:949–51 https://www.ncbi.nlm.nih.gov/pubmed/15482623 15482623 | Study Design, Intervention/Exposure
369 | Trichopoulou, A, Bamia, C, Norat, T, Overvad, K, Schmidt, EB, Tjonneland, A, Halkjaer, J, Clavel-Chapelon, F, Vercambre, MN, Boutron-Ruault, MC, Linseisen, J, Rohrmann, S, Boeing, H, Weikert, C, Benetou, V, Psaltopoulou, T, Orfanos, P, Boffetta, P, Masala, G, Pala, V, Panico, S, Tumino, R, Sacerdote, C, Bueno-de-Mesquita, HB, Ocke, MC, Peeters, PH, Van der Schouw, YT, Gonzalez, C, Sanchez, MJ, Chirlaque, MD, Moreno, C, Larranaga, N, Van Guelpen, B, Jansson, JH, Bingham, S, Khaw, KT, Spencer, EA, Key, T, Riboli, E, Trichopoulos, D. Modified Mediterranean diet and survival after myocardial infarction: the EPIC-Elderly study. Eur J Epidemiol. 2007. 22:871–81 https://www.ncbi.nlm.nih.gov/pubmed/17926134 17926134 | Health Status
370 | Trichopoulou, A. Mediterranean diet, traditional foods, and health: evidence from the Greek EPIC cohort. Food Nutr Bull. 2007. 28:236–40 https://www.ncbi.nlm.nih.gov/pubmed/24683683 24683683 | Study design
371 | Trichopoulou, A. Olive oil, Mediterranean diet and health. Clinica e Investigacion en Arteriosclerosis. 2010. 22:19–20 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L361246403 | Study Design
372 | Trichopoulou, A.,Psaltopoulou, T.,Orfanos, P.,Hsieh, C. C.,Trichopoulos, D. 2007. Low-carbohydrate-high-protein diet and long-term survival in a general population cohort Eur J Clin Nutr, 61(5): 575–81. https://www.ncbi.nlm.nih.gov/pubmed/17136037 17136037 | Intervention/Exposure: did not describe the macronutrient distribution of the diet for the categories analyzed
373 | Turati, F, Dilis, V, Rossi, M, Lagiou, P, Benetou, V, Katsoulis, M, Naska, A, Trichopoulos, D, La Vecchia, C, Trichopoulou, A. Glycemic load and coronary heart disease in a Mediterranean population: the EPIC Greek cohort study. Nutr Metab Cardiovasc Dis. 2015. 25:336–42 https://www.ncbi.nlm.nih.gov/pubmed/25638596 25638596 | Outcome
374 | Turunen, AW, Verkasalo, PK, Kiviranta, H, Pukkala, E, Jula, A, Mannisto, S, Rasanen, R, Marniemi, J, Vartiainen, T. Mortality in a cohort with high fish consumption. Int J Epidemiol. 2008. 37:1008–17 https://www.ncbi.nlm.nih.gov/pubmed/18579573 18579573 | Intervention/Exposure
375 | van der Pols, JC, Gunnell, D, Williams, GM, Holly, JM, Bain, C, Martin, RM. Childhood dairy and calcium intake and cardiovascular mortality in adulthood: 65-year follow-up of the Boyd Orr cohort. Heart. 2009. 95:1600–6 https://www.ncbi.nlm.nih.gov/pubmed/19643770 19643770 | Intervention/Exposure
376 | Vasto, S, Buscemi, S, Barera, A, Di Carlo, M, Accardi, G, Caruso, C. Mediterranean diet and healthy ageing: a Sicilian perspective. Gerontology. 2014. 60:508–18 https://www.ncbi.nlm.nih.gov/pubmed/25170545 25170545 | Study Design
377 | Vergnaud, AC, Romaguera, D, Peeters, PH, Van Gils, CH, Chan, DSM, Romieu, I, Freisling, H, Ferrari, P, Clavel-Chapelon, F, Fagherazzi, G, Dartois, L, Li, K, Tikk, K, Bergmann, MM, Boeing, H, TjÃ¸nneland, A, Olsen, A, Overvad, K, Dahm, CC, Redondo, ML, Agudo, A, Sanchez, MJ, Amiano, P, Chirlaque, MD, Ardanaz, E, Khaw, KT, Wareham, NJ, Crowe, F, Trichopoulou, A, Orfanos, P, Trichopoulos, D, Masala, G, Sieri, S, Tumino, R, Vineis, P, Panico, S, Bueno-de-Mesquita, HB, Ros, MM, May, A, Wirfalt, E, Sonestedt, E, Johansson, I, Hallmans, G, Lund, E, Weiderpass, E, Parr, CL, Riboli, E, Norat, T. Adherence to the World Cancer Research Fund/American Institute for Cancer Research guidelines and risk of death in Europe: Results from the European Prospective Investigation into Nutrition and Cancer cohort study1-5. American Journal of Clinical Nutrition. 2013. 97:1107–1120 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L368825151 | Intervention/Exposure
378 | Veronese, N, Li, Y, Manson, JE, Willett, WC, Fontana, L, Hu, FB. Combined associations of body weight and lifestyle factors with all cause and cause specific mortality in men and women: prospective cohort study. Bmj. 2016. 355:i5855 https://www.ncbi.nlm.nih.gov/pubmed/27884868 27884868 | Intervention/Exposure
379 | Virtanen, HEK, Voutilainen, S, Koskinen, TT, Mursu, J, Kokko, P, Ylilauri, MPT, Tuomainen, TP, Salonen, JT, Virtanen, JK. Dietary proteins and protein sources and risk of death: the Kuopio Ischaemic Heart Disease Risk Factor Study. Am J Clin Nutr. 2019. 109:1462–1471 https://www.ncbi.nlm.nih.gov/pubmed/30968137 30968137 | Outcome
380 | Virtanen, HEK, Voutilainen, S, Koskinen, TT, Mursu, J, Tuomainen, TP, Virtanen, JK. Intake of Different Dietary Proteins and Risk of Heart Failure in Men: The Kuopio Ischaemic Heart Disease Risk Factor Study. Circ Heart Fail. 2018. 11:e004531 https://www.ncbi.nlm.nih.gov/pubmed/29844244 29844244 | Outcome
381 | Wang, DD, Li, Y, Afshin, A, Springmann, M, Mozaffarian, D, Stampfer, MJ, Hu, FB, Murray, CJL, Willett, WC. Global Improvement in Dietary Quality Could Lead to Substantial Reduction in Premature Death. J Nutr. 2019. 149:1065–1074 https://www.ncbi.nlm.nih.gov/pubmed/31049577 31049577 | Study Design, Intervention/Exposure, Outcome, Country
382 | Wang, DD, Li, Y, Chiuve, SE, Stampfer, MJ, Manson, JE, Rimm, EB, Willett, WC, Hu, FB. Association of Specific Dietary Fats With Total and Cause-Specific Mortality. JAMA Intern Med. 2016. 176:1134–45 https://www.ncbi.nlm.nih.gov/pubmed/27379574 27379574 | Intervention/Exposure
383 | Wang, JB, Fan, JH, Dawsey, SM, Sinha, R, Freedman, ND, Taylor, PR, Qiao, YL, Abnet, CC. Dietary components and risk of total, cancer and cardiovascular disease mortality in the Linxian Nutrition Intervention Trials cohort in China. Sci Rep. 2016. 6:22619 https://www.ncbi.nlm.nih.gov/pubmed/26939909 26939909 | Intervention/Exposure
384 | Waskiewicz, A, Piotrowski, W, Szostak-Wegierek, D, Cicha-Mikolajczyk, A. Relationship between 28-year food consumption trends and the 10-year global risk of death due to cardiovascular diseases in the adult Warsaw population. Kardiol Pol. 2015. 73:650–5 https://www.ncbi.nlm.nih.gov/pubmed/26310505 26310505 | Intervention/Exposure, Outcome
385 | White, J, Greene, G, Kivimaki, M, Batty, GD. Association between changes in lifestyle and ACM: the Health and Lifestyle Survey. J Epidemiol Community Health. 2018. 72:711–714 https://www.ncbi.nlm.nih.gov/pubmed/29602792 29602792 | Intervention/Exposure
386 | Whitley, E, Batty, GD, Hunt, K, Popham, F, Benzeval, M. The role of health behaviours across the life course in the socioeconomic patterning of ACM: the west of Scotland twenty-07 prospective cohort study. Annals of behavioral medicine: a publication of the Society of Behavioral Medicine. 2014. 47:148–157 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L373991272 24072618 | Intervention/Exposure
387 | Willcox, BJ, Willcox, DC, Todoriki, H, Fujiyoshi, A, Yano, K, He, Q, Curb, JD, Suzuki, M. Caloric restriction, the traditional Okinawan diet, and healthy aging: the diet of the world’s longest-lived people and its potential impact on morbidity and life span. Ann N Y Acad Sci. 2007. 1114:434–55 https://www.ncbi.nlm.nih.gov/pubmed/17986602 17986602 | Outcome
388 | Willcox, BJ, Yano, K, Chen, R, Willcox, DC, Rodriguez, BL, Masaki, KH, Donlon, T, Tanaka, B, Curb, JD. How much should we eat? The association between energy intake and mortality in a 36-year follow-up study of Japanese-American men. J Gerontol A Biol Sci Med Sci. 2004. 59:789–95 https://www.ncbi.nlm.nih.gov/pubmed/15345727 15345727 | Intervention/Exposure
389 | Woo, J, Ho, SC, Yu, AL. Lifestyle factors and health outcomes in elderly Hong Kong chinese aged 70 years and over. Gerontology. 2002. 48:234–40 https://www.ncbi.nlm.nih.gov/pubmed/12053113 12053113 | Intervention/Exposure
390 | Woodside, JV, Yarnell, JW, Patterson, CC, Arveiler, D, Amouyel, P, Ferrieres, J, Kee, F, Evans, A, Bingham, A, Ducimetiere, P. Do lifestyle behaviours explain socioeconomic differences in ACM, and fatal and non-fatal cardiovascular events? Evidence from middle aged men in France and Northern Ireland in the PRIME Study. Prev Med. 2012. 54:247–53 https://www.ncbi.nlm.nih.gov/pubmed/22306980 22306980 | Intervention/Exposure
391 | Xu, M, Huang, T, Lee, AW, Qi, L, Cho, S. Ready-to-Eat Cereal Consumption with Total and Cause-Specific Mortality: Prospective Analysis of 367,442 Individuals. J Am Coll Nutr. 2016. 35:217–23 https://www.ncbi.nlm.nih.gov/pubmed/26595440 26595440 | Intervention/Exposure
392 | Yaghjyan, L, Wijayabahu, AT, Egan, KM. RE: The association between dietary quality and overall and cancer-specific mortality among cancer survivors, NHANES III. JNCI Cancer Spectrum. 2018. 2: http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L625251089 | Study Design
393 | Yu, D, Zhang, X, Xiang, YB, Yang, G, Li, H, Gao, YT, Zheng, W, Shu, XO. Adherence to dietary guidelines and mortality: A report from prospective cohort studies of 134,000 Chinese adults in urban Shanghai. American Journal of Clinical Nutrition. 2014. 100:693–700 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L373681291 | Country
394 | Zahra, A, Lee, EW, Sun, LY, Park, JH. Cardiovascular disease and diabetes mortality, and their relation to socio-economical, environmental, and health behavioural factors in worldwide view. Public Health. 2015. 129:385–95 https://www.ncbi.nlm.nih.gov/pubmed/25724438 25724438 | Study Design, Outcome, Country
395 | Zamora-Ros, R, Cayssials, V, Cleries, R, Redondo, ML, Sanchez, MJ, Rodriguez-Barranco, M, Sanchez-Cruz, JJ, Mokoroa, O, Gil, L, Amiano, P, Navarro, C, Chirlaque, MD, Huerta, JM, Barricarte, A, Ardanaz, E, Moreno-Iribas, C, Agudo, A. Moderate egg consumption and all-cause and specific-cause mortality in the Spanish European Prospective into Cancer and Nutrition (EPIC-Spain) study. Eur J Nutr. 2018. https://www.ncbi.nlm.nih.gov/pubmed/29905885 | Intervention/Exposure
396 | Zhang, QL, Zhao, LG, Zhang, W, Li, HL, Gao, J, Han, LH, Zheng, W, Shu, XO, Xiang, YB. Combined Impact of Known Lifestyle Factors on Total and Cause-Specific Mortality among Chinese Men: A Prospective Cohort Study. Scientific reports. 2017. 7:5293 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L625802125 28706246 | Country
397 | Zhang, Y, Zhuang, P, He, W, Chen, JN, Wang, WQ, Freedman, ND, Abnet, CC, Wang, JB, Jiao, JJ. Association of fish and long-chain omega-3 fatty acids intakes with total and cause-specific mortality: prospective analysis of 421 309 individuals. J Intern Med. 2018. 284:399–417 https://www.ncbi.nlm.nih.gov/pubmed/30019399 30019399 | Intervention/Exposure
398 | Zhou, M, Wang, H, Zeng, X, Yin, P, Zhu, J, Chen, W, Li, X, Wang, L, Wang, L, Liu, Y, Liu, J, Zhang, M, Qi, J, Yu, S, Afshin, A, Gakidou, E, Glenn, S, Krish, VS, Miller-Petrie, MK, Mountjoy-Venning, WC, Mullany, EC, Redford, SB, Liu, H, Naghavi, M, Hay, SI, Wang, L, Murray, CJL, Liang, X. Mortality, morbidity, and risk factors in China and its provinces, 1990-2017: a systematic analysis for the Global Burden of Disease Study 2017. Lancet. 2019. 394:1145–1158 https://www.ncbi.nlm.nih.gov/pubmed/31248666 31248666 | Study Design, Intervention/Exposure
399 | Zhuang, P, Cheng, L, Wang, J, Zhang, Y, Jiao, J. Saturated Fatty Acid Intake Is Associated with Total Mortality in a Nationwide Cohort Study. J Nutr. 2019. 149:68–77 https://www.ncbi.nlm.nih.gov/pubmed/30608597 30608597 | Intervention/Exposure
400 | Zhuang, P, Zhang, Y, He, W, Chen, X, Chen, J, He, L, Mao, L, Wu, F, Jiao, J. Dietary Fats in Relation to Total and Cause-Specific Mortality in a Prospective Cohort of 521 120 Individuals With 16 Years of Follow-Up. Circ Res. 2019. 124:757–768 https://www.ncbi.nlm.nih.gov/pubmed/30636521 30636521 | Intervention/Exposure

xviii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xix Institute of Medicine. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington (DC): The National Academies Press; 2002.

xx Macronutrient percent of energy outside of the AMDR are as follows:

- Carbohydrate for all age groups: <45 or >65 percent of energy;
- Protein for children, 1-3y: <5 or >20 percent of energy, Protein for children, 4-18y: <10 or >30 percent of energy, Protein for adults, age 19y and older: <10 or >35 percent of energy;
- Fat for children, 1-3y: <30 or >40 percent of energy, Fat for children, 4-18y: <25 or >35 percent of energy, Fat for adults, age 19y and older: <20 or >35 percent of energy.

xxi The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead ( The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups ).