# List of abbreviations

Abbreviation: Full name
AA: Arachidonic acid
ALA: Alpha-linolenic acid
BMI: Body mass index
CAD: Coronary artery disease
CHD: Coronary heart disease
CNPP: Center for Nutrition Policy and Promotion
CVD: Cardiovascular disease
DHA: Docosahexaenoic acid
DISC: Dietary Intervention Study in Children
DPA: Docosapentaenoic acid
EPA: Eicosapentaenoic acid
FFQ: Food frequency questionnaire
FNS: Food and Nutrition Service
HDI: Human Development Index
HDL: High-density lipoprotein
HHS: United States Department of Health and Human Services
LA: Linoleic acid
LDL: Low-density lipoprotein
MI: Myocardial infarction
MUFA: Monounsaturated fatty acid
N: Sample size
n-3: Omega-3
n-6: Omega-6
NCC: Nested case-control
NESR: Nutrition Evidence Systematic Review
NRCT: Non-randomized controlled trial
OASH: Office of the Assistant Secretary for Health
ODPHP: Office of Disease Prevention and Health Promotion
PAD: Peripheral artery disease
PCS: Prospective cohort study
PUFA: Polyunsaturated fatty acid
RCT: Randomized controlled trial
SFA: Saturated fatty acid
STRIP: Special Turku Coronary Risk Factor Intervention Project
UFA: Unsaturated fatty acid
U.K.: United Kingdom
U.S.: United States
USDA: United States Department of Agriculture