# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^xii^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C: Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol are described in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 9. Dietary Fats and Seafood.

The systematic review described in this document builds on evidence reviewed by the 2015 Dietary Guidelines Advisory Committee. Information about the 2015 Dietary Guidelines Advisory Committee’s review of the evidence for the question “What is the relationship between intake of saturated fat and risk of cardiovascular disease?” can be found in their report^xiii^ (see Part D. Chapter 6: Cross-Cutting Topics of Public Health Importance, page 337).

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature searches and screening plan
- Literature searches and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on what is the relationship between types of dietary fat consumed and risk of cardiovascular disease? For this systematic review, the target population considered was infants and toddlers (birth to 24 months), children and adolescents (ages 2-18 years), adults (ages 19-64 years), and older adults (ages 65 years and older), healthy and/or at risk for chronic disease for the intervention or exposure. The interventions or exposures considered were the consumption of type(s) of dietary fats and their comparators were the consumption of different type(s), source(s), amount(s), and/or proportion(s) of dietary fats, or replacement with dietary carbohydrate and/or protein (the types of dietary fat to be considered include saturated fats, omega-3 and omega-6 polyunsaturated fatty acids, monounsaturated fatty acids, and dietary cholesterol; the source, amount, proportion, and replacement with other dietary fats and/or carbohydrate will be considered in analyses). The intermediate outcomes considered were blood pressure (systolic and diastolic; ages 18 years or younger), total cholesterol (TC), LDL-cholesterol, HDL-cholesterol, and triglycerides for all ages. The endpoint outcomes considered were cardiovascular disease (myocardial infarction, coronary heart disease, coronary artery disease, congestive heart failure, peripheral artery disease), stroke, venous thrombosis, and cardiovascular disease-related mortality. The population for the endpoint outcomes were adults 19 years and older. The key confounders were sex, age, race/ethnicity, socioeconomic status, total energy intake, alcohol intake (in adults >18 years), physical activity, smoking (in adults >18 years), and family history of cardiovascular disease or diabetes. Other factors to be considered were carbohydrate and protein intake, other types of dietary fats, baseline cardiovascular disease risk category (high, moderate, low), duration or intensity of intervention, n-3 PUFA supplement use, and anthropometry.

## LITERATURE SEARCHES AND SCREENING PLAN

### Inclusion and exclusion criteria

This table (Table 11) provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature searches were included in or excluded from the systematic review

Table 11 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials (RCTs); - Non-randomized controlled trials (NRCTs), including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Consumption of type(s) of dietary fats; ○ Types of dietary fat to be considered included saturated, omega-3 and omega-6 polyunsaturated, monounsaturated fatty acids, and dietary cholesterol.; ○ The source, amount, proportion, and replacement with other dietary fats and/or carbohydrate/protein will also be considered in analyses | - Studies that do not assess consumption of type(s) of dietary fats (e.g., studies that only examined biomarkers for consumption); - Studies that only assess total fat intake or overall macronutrient composition; - Studies that only assess trans fat; - Studies that examine food products not widely available to U.S. consumers; - Studies that exclusively assess intake of fat from supplements or fish oils; - Human milk and/or infant formula as the only source of dietary fat; - Multi-component interventions that do not isolate the impact of type of fat
Comparator | - Consumption of different type(s), source(s), amount(s), and/or proportion(s) of dietary fats, or replacement with dietary carbohydrates and/or protein | - No comparator
Outcomes | [underlined: Intermediate Outcomes (Children: all study designs; Adults: interventions only)]; - Blood pressure (systolic and diastolic) (≤18y of age); - Total Cholesterol (TC); - LDL Cholesterol; - HDL Cholesterol; - Triglycerides; [underlined: Endpoint Outcomes]; - Cardiovascular disease (myocardial infarction, coronary heart disease, coronary artery disease, congestive heart failure, peripheral artery disease); - Stroke; - Venous thrombosis; - Cardiovascular disease mortality | - Studies that only assess post-prandial lipid levels (i.e., total, LDL, and HDL cholesterol, and/or triglycerides); - Studies that only assess serum lipid ratios (i.e., TC:HDL, LDL:HDL ratios); - Blood pressure in adults (>18y of age); - Intermediate outcomes in observational studies conducted in adults (>18y of age)
Study duration | - Observational studies: Any duration; - RCTs and NRCTs: Interventions ≥4wk in duration | - RCTs and NRCTs:Interventions <4wk in duration
Date of publication | - January 1990 to October 2019 for articles on types of dietary fat consumed by children and adolescents and risk of cardiovascular disease.; - January 2010 to October 2019 for articles on types of dietary fat consumed by adults and risk of cardiovascular disease.^*^ | - Articles published prior to January 1990 on types of fat consumed by children and adolescents and risk of cardiovascular disease.; - Articles published before 2010 on types of fat consumed by adults and risk of cardiovascular disease.; - Articles published after October 2019
Publication status | - Articles that have been peer-reviewed | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, and conference proceedings
Language of publication | - Articles published in English | - Articles published in languages other than English
Country^†^ | - Studies conducted in countries ranked as high or very high human development | - Studies conducted in countries ranked as medium or Lower human development
Study participants | - Human participants (male and/or female); - Females who are pregnant and/or lactating | - Non-human subjects (e.g., animal models or in-vitro models)
Age of study participants | - Age at intervention or exposure:; ○ Infants and toddlers (birth to 24 months); ○ Children and adolescents (ages 2-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older); - Age at intermediate outcomes:; ○ Infants and toddlers ages (birth to 24 months); ○ Children and adolescents (ages 2-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older); - Age at endpoint outcomes:; ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older) | - Age at endpoint outcome:; ○ Infants and toddlers (birth to 24 months); ○ Children and adolescents (ages 2-18 years)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that exclusively enroll participants with high blood pressure or high cholesterol and are evaluating cardiovascular disease endpoint outcomes; - Studies that enroll some participants diagnosed with cardiovascular disease endpoint outcomes.; - Studies that enroll some participants diagnosed with a disease or hospitalized with and illness or injury; - Studies that enroll infants born full-term (≥37 weeks and 0/7 days gestational age); - Studies that enroll some infants born preterm (gestational age <37 weeks and 0/7 days), infants with Low birth weight (<2500g), and/or infants born small for gestational age | - Studies that exclusively enroll participants diagnosed with a disease (e.g., diabetes, renal disease), or hospitalized with an illness or injury (For this criterion, studies that exclusively enroll participants with obesity will not be excluded); - Studies that exclusively enroll participants with cardiovascular disease endpoint outcomes (i.e., studies that aim to treat participants who have already been diagnosed with cardiovascular disease); - Studies that exclusively enroll participants with high blood lipids (e.g., TC, LDL cholesterol, HDL cholesterol, or triglycerides) and are evaluating any blood lipid intermediate outcome (i.e., studies that aim to treat participants who already have high cholesterol or blood lipids)

* This systematic review builds upon the 2015 Dietary Guidelines Advisory Committee report that considered evidence in adults preceding January 2010.

† The Human Development classification was based on the Human Development Index (HDI) ranking (1) from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank (2) was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).

### Electronic databases and search terms

Listed below are the databases searched to identify all potentially relevant articles that have been published to address the systematic review question. Two search strategies were developed and implemented each in four databases (PubMed, Cochrane Central Register of Controlled Trials (CENTRAL), Embase and Cumulative Index of Nursing and Allied Health Literature (CINAHL) to conduct this systematic review.

#### Search strategy 1: Search strategy to capture the literature on types of dietary fats and risk of cardiovascular disease for children and adolescents from 1990-2009

##### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: October 30, 2019
- Date range searched: January 1, 1990-December 31, 2009
- Search Terms:
  - #1 - “Dietary Fats”[Mesh] OR dietary fat* OR diet fat* OR dietary lipid* OR fat consumption* OR fat intake* OR “Fatty Acids”[Mesh:noexp] OR fatty acid* OR saturated fat* OR “Fatty Acids, Monounsaturated”[Mesh] OR monounsaturated fat* OR mono-unsaturated fat* OR polyunsaturated fat* OR poly-unsaturated fat* OR unsaturated fat* OR unsaturated fatty acid* OR “Fatty Acids, Omega-3”[Mesh] OR omega-3[tiab] OR N-3 fatty acid* OR “Fatty Acids, Omega-6”[Mesh] OR omega-6 OR N-6 fatty acid* OR MUFA* OR PUFA* OR “Cholesterol, Dietary”[Mesh] OR dietary cholesterol* OR alpha-linolenic acid* OR eicosapentaenoic acid* OR docosahexaenoic acid* OR linoleic acid* OR alpha-linolenic acid* OR arachidonic acid* OR “Fats, Unsaturated”[Mesh] OR milk fat*[tiab] OR “Butter”[Mesh] OR butter[tiab] OR Ghee[tiab] OR “Margarine”[Mesh] OR margarine[tiab] OR dietary oil* OR “Plant Oils”[Mesh] OR plant oil* OR “Fish Oils”[Mesh] OR fish oil* OR olive oil* OR corn oil* OR cottonseed oil* OR cotton seed oil* OR safflower oil* OR sesame oil* OR soybean oil* OR soya-bean oil* OR linseed oil* OR canola oil* OR peanut oil* OR coconut oil* OR edible oil* OR palm oil* OR fish oil* OR maize oil* OR oleic acid* OR ((fat[tiab] OR fatty[tiab]) AND (saturat* OR unsatur* OR monounsatur* OR polyunsatur* OR poly-unsatur* OR linolenic acid* OR “Milk”[Mesh] OR milk[tiab] OR “Infant Formula”[Mesh] OR infant formula*[tiab]))
  - #2 - “Cardiovascular Diseases”[Mesh:noexp] OR cardiovascular disease*[tiab] OR coronary artery disease[tiab] OR heart disease*[tiab] OR “Heart Failure”[Mesh] OR heart failure[tiab] OR “Myocardial Infarction”[Mesh] OR myocardial infarction*[tiab] OR “Myocardial Ischemia”[Mesh] OR Myocardial Ischemia*[tiab] OR “Stroke”[Mesh] OR stroke[tiab] OR angina[tiab] OR heart attack[tiab] OR “Cardiovascular System”[Mesh] OR “cardiometabolic health” OR cardiovascular health[tiab] OR “cardiac health” OR “cardiovascular biomarkers” OR “Venous Thrombosis”[Mesh] OR venous thrombosis[tiab] OR hypertension[tiab] OR high blood pressure[tiab] OR “Lipids/blood”[Mesh] OR “Cholesterol, HDL”[Mesh] OR HDL cholesterol[tiab] OR “Cholesterol, LDL”[Mesh] OR LDL cholesterol[tiab] OR total cholesterol[tiab] OR “Triglycerides”[Mesh] OR triglycerides[tiab]
  - #3 - “Child”[Mesh] OR child[tiab] OR children[tiab] OR youth* OR “Adolescent”[Mesh] OR adolescence[tiab] OR adolescent* OR teen[tiab] OR teens[tiab] OR teenager* OR preteen* OR pre-teen* OR pre-adolesc* OR preadolesc* OR preschool* OR “Pediatrics”[Mesh] OR pediatric* OR paediatric* OR “Infant”[Mesh] OR Infan*[tiab] OR newborn*[tiab] OR new-born*[tiab] OR perinat*[tiab] OR neonat* OR prematur* OR preterm* OR baby[tiab] OR babies[tiab] OR toddler*[tiab] OR boy[tiab] OR boys[tiab] OR girl[tiab] OR girls[tiab] OR schoolchild* OR middle school* OR high school* OR juvenile[tiab] OR pubescent[tiab] OR pre pubescent[tiab] OR prepubescent[tiab] OR kid[tiab] OR kids[tiab] OR early childhood[tiab] OR early years[tiab] OR pre-k[tiab] OR pre-primary[tiab] OR under five*[tiab] OR young child*[tiab] OR head start[tiab] OR prekindergarten[tiab] OR pre-kindergarten[tiab]
  - #4- (#1 AND #2 AND #3)
  - #5 - (#1 AND #2 AND #3) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 1990/01/01 to 2009/12/31; English

##### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: October 30, 2019
- Date range searched: January 1, 1990-December 31, 2009
- Search Terms:
  - #1 - [mh “Dietary Fats”] OR [mh ^“Fatty Acids”] OR [mh “Fatty Acids, Monounsaturated”] OR [mh “Fatty Acids, Omega-3”] OR [mh “Fatty Acids, Omega-6”] OR [mh “Cholesterol, Dietary”] OR [mh “Fats, Unsaturated”] OR [mh Butter] OR [mh Margarine] OR [mh “Plant Oils”] OR [mh “Fish Oils”]
  - #2 - (“dietary fat*” OR “diet fat*” OR “dietary lipid*” OR “fat consumption*” OR “fat intake*” OR “fatty acid*” OR “saturated fat*” OR “monounsaturated fat*” OR “mono-unsaturated fat*” OR “polyunsaturated fat*” OR “poly-unsaturated fat*” OR “unsaturated fat*” OR “unsaturated fatty acid*” OR omega-3 OR “N-3 fatty acid*” OR omega-6 OR “N-6 fatty acid*” OR MUFA* OR PUFA* OR “dietary cholesterol*” OR “alpha-linolenic acid*” OR “eicosapentaenoic acid*” OR “docosahexaenoic acid*” OR “linoleic acid*” OR “alpha-linolenic acid*” OR “arachidonic acid*” OR “milk fat*” OR butter OR Ghee OR margarine OR “dietary oil*” OR “plant oil*” OR “fish oil*” OR “olive oil*” OR “corn oil*” OR “cottonseed oil*” OR “cotton seed oil*” OR “safflower oil*” OR “sesame oil*” OR “soybean oil*” OR “soya-bean oil*” OR “linseed oil*” OR “canola oil*” OR “peanut oil*” OR “coconut oil*” OR “edible oil*” OR “palm oil*” OR “fish oil*” OR “maize oil*” OR “oleic acid*”):ti,ab,kw
  - #3 - ((fat OR fatty) NEAR/6 (saturat* OR unsatur* OR monounsatur* OR polyunsatur* OR poly-unsatur* OR “linolenic acid*” OR [mh Milk] OR milk OR [mh “Infant Formula”] OR “infant formula*”)):ti,ab,kw
  - #4 - #1 OR #2 OR #3
  - #5 - [mh ^“Cardiovascular Diseases”] OR [mh “Heart Failure”] OR [mh “Myocardial Ischemia”] OR [mh “Myocardial Infarction”] OR [mh Stroke] OR [mh “Cardiovascular System”] OR [mh “Venous Thrombosis”] OR [mh Lipids/BL] OR [mh “Cholesterol, HDL”] OR [mh “Cholesterol, LDL”] OR [mh Triglycerides]
  - #6 - (“cardiovascular disease*” OR “coronary artery disease” OR “heart disease*” OR “heart failure” OR “myocardial infarction*” OR “myocardial ischemia*” OR stroke OR angina OR “heart attack” OR “cardiometabolic health” OR “cardiovascular health” OR “cardiac health” OR “cardiovascular biomarkers” OR “venous thrombosis” OR hypertension OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR triglycerides):ti,ab,kw”
  - #7 - #5 OR #6
  - #8 - [mh Child] OR [mh Adolescent] OR [mh Pediatrics] OR [mh Infant]
  - #9 - (Child OR children OR youth* OR adolescence OR adolescent* OR teen OR teens OR teenager* OR preteen* OR pre-teen* OR pre-adolesc* OR preadolesc* OR preschool* OR pediatric* OR paediatric* OR Infan* OR newborn* OR new-born* OR perinat* OR neonat* OR prematur* OR preterm* OR baby OR babies OR toddler* OR boy OR boys OR girl OR girls OR schoolchild* OR “middle school*” OR “high school*” OR juvenile OR pubescent OR “pre pubescent” OR prepubescent OR kid OR kids OR “early childhood” OR “early years” OR pre-k OR pre-primary OR “under five*” OR “young child*” OR “head start” OR prekindergarten OR pre-kindergarten):ti,ab,kw
  - #10 - #8 OR #9
  - #11 - #4 AND #7 AND #10” with Publication Year from 1990 to 2009, in Trials (Word variations have been searched)

##### Embase

- Provider: Elsevier
- Date(s) Searched: October 30, 2019
- Date range searched: January 1, 1990-December 31, 2009
- Search Terms:
  - #1 - ‘edible oil’/exp OR ‘fatty acid’/de OR ‘monounsaturated fatty acid’/de OR ‘omega 3 fatty acid’/de OR ‘omega 6 fatty acid’/de OR ‘cholesterol intake’/de OR ‘unsaturated fatty acid’/exp OR ‘butter’/de OR ‘margarine’/de OR ‘vegetable oil’/exp OR ‘fish oil’/de
  - #2 - ‘dietary fat*’:ab,ti OR ‘diet fat*’:ab,ti OR ‘dietary lipid*’:ab,ti OR ‘fat consumption*’:ab,ti OR ‘fat intake*’:ab,ti OR ‘fatty acid*’:ab,ti OR ‘saturated fat*’:ab,ti OR ‘monounsaturated fat*’:ab,ti OR ‘mono-unsaturated fat*’:ab,ti OR ‘polyunsaturated fat*’:ab,ti OR ‘poly-unsaturated fat*’:ab,ti OR ‘unsaturated fat*’:ab,ti OR ‘unsaturated fatty acid*’:ab,ti OR ‘omega 3’:ab,ti OR ‘n-3 fatty acid*’:ab,ti OR ‘omega 6’:ab,ti OR ‘n-6 fatty acid*’:ab,ti OR mufa*:ab,ti OR pufa*:ab,ti OR ‘dietary cholesterol*’:ab,ti OR ‘eicosapentaenoic acid*’:ab,ti OR ‘docosahexaenoic acid*’:ab,ti OR ‘linoleic acid*’:ab,ti OR ‘alpha-linolenic acid*’:ab,ti OR ‘arachidonic acid*’:ab,ti OR ‘milk fat*’:ab,ti OR butter:ab,ti OR ghee:ab,ti OR margarine:ab,ti OR ‘dietary oil*’:ab,ti OR ‘plant oil*’:ab,ti OR ‘olive oil*’:ab,ti OR ‘corn oil*’:ab,ti OR ‘cottonseed oil*’:ab,ti OR ‘cotton seed oil*’:ab,ti OR ‘safflower oil*’:ab,ti OR ‘sesame oil*’:ab,ti OR ‘soybean oil*’:ab,ti OR ‘soya-bean oil*’:ab,ti OR ‘linseed oil*’:ab,ti OR ‘canola oil*’:ab,ti OR ‘peanut oil*’:ab,ti OR ‘coconut oil*’:ab,ti OR ‘edible oil*’:ab,ti OR ‘palm oil*’:ab,ti OR ‘fish oil*’:ab,ti OR ‘maize oil*’:ab,ti OR ‘oleic acid*’:ab,ti
  - #3 - ((fat OR fatty) NEAR/6 (saturat* OR unsatur* OR monounsatur* OR polyunsatur* OR poly-unsatur* OR ‘linolenic acid*’ OR milk OR ‘infant formula*’)):ab,ti
  - #4 - #1 OR #2 OR #3
  - #5 - ‘cardiovascular disease’/de OR ‘heart failure’/exp OR ‘heart muscle ischemia’/exp OR ‘heart infarction’/exp OR ‘cerebrovascular accident’/exp OR ‘cardiovascular system’/exp OR ‘vein thrombosis’/exp OR ‘high density lipoprotein cholesterol’/de OR ‘low density lipoprotein cholesterol’/de OR ‘triacylglycerol’/exp
  - #6 - ‘cardiovascular disease*’:ab,ti OR ‘coronary artery disease’:ab,ti OR ‘heart disease*’:ab,ti OR ‘heart failure’:ab,ti OR ‘myocardial infarction*’:ab,ti OR ‘myocardial ischemia*’:ab,ti OR stroke:ab,ti OR angina:ab,ti OR ‘heart attack’:ab,ti OR ‘cardiometabolic health’:ab,ti OR ‘cardiovascular health’:ab,ti OR ‘cardiac health’:ab,ti OR ‘cardiovascular biomarkers’:ab,ti OR ‘venous thrombosis’:ab,ti OR hypertension:ab,ti OR ‘high blood pressure’:ab,ti OR ‘hdl cholesterol’:ab,ti OR ‘ldl cholesterol’:ab,ti OR ‘total cholesterol’:ab,ti OR triglycerides:ab,ti
  - #7 - #5 OR #6
  - #8 - ‘child’/exp OR ‘adolescent’/exp OR ‘pediatrics’/de
  - #9 - child:ab,ti OR children:ab,ti OR youth*:ab,ti OR adolescence:ab,ti OR adolescent*:ab,ti OR teen:ab,ti OR teens:ab,ti OR teenager*:ab,ti OR preteen*:ab,ti OR ‘pre teen*’:ab,ti OR ‘pre adolesc*’:ab,ti OR preadolesc*:ab,ti OR preschool*:ab,ti OR pediatric*:ab,ti OR paediatric*:ab,ti OR infan*:ab,ti OR newborn*:ab,ti OR ‘new born*’:ab,ti OR perinat*:ab,ti OR neonat*:ab,ti OR prematur*:ab,ti OR preterm*:ab,ti OR baby:ab,ti OR babies:ab,ti OR toddler*:ab,ti OR boy:ab,ti OR boys:ab,ti OR girl:ab,ti OR girls:ab,ti OR schoolchild*:ab,ti OR ‘middle school*’:ab,ti OR ‘high school*’:ab,ti OR juvenile:ab,ti OR pubescent:ab,ti OR ‘pre pubescent’:ab,ti OR prepubescent:ab,ti OR kid:ab,ti OR kids:ab,ti OR ‘early childhood’:ab,ti OR ‘early years’:ab,ti OR ‘pre k’:ab,ti OR ‘pre primary’:ab,ti OR ‘under five*’:ab,ti OR ‘young child*’:ab,ti OR ‘head start’:ab,ti OR prekindergarten:ab,ti OR ‘pre kindergarten’:ab,ti
  - #10 - #8 OR #9
  - #11 - #4 AND #7 AND #10 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1990-2009]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

##### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) Searched: October 30, 2019
- Date range searched: January 1, 1990-December 31, 2009
- Search Terms:
  - #S1 - (MH “Dietary Fats+”) OR (MH “Fatty Acids”) OR (MH “Fatty Acids, Monounsaturated+”) OR (MH “Fatty Acids, Omega-3+”) OR (MH “Fatty Acids, Omega-6+”) OR (MH “Cholesterol, Dietary”) OR (MH “Fats, Unsaturated+”) OR (MH “Butter”) OR (MH “Margarine”) OR (MH “Plant Oils+”) OR (MH “Fish Oils+”)
  - #S2 - “dietary fat*” OR “diet fat*” OR “dietary lipid*” OR “fat consumption*” OR “fat intake*” OR “fatty acid*” OR “saturated fat*” OR “monounsaturated fat*” OR “mono-unsaturated fat*” OR “polyunsaturated fat*” OR “poly-unsaturated fat*” OR “unsaturated fat*” OR “unsaturated fatty acid*” OR omega-3 OR “N-3 fatty acid*” OR omega-6 OR “N-6 fatty acid*” OR MUFA* OR PUFA* OR “dietary cholesterol*” OR “alpha-linolenic acid*” OR “eicosapentaenoic acid*” OR “docosahexaenoic acid*” OR “linoleic acid*” OR “alpha-linolenic acid*” OR “arachidonic acid*” OR “milk fat*” OR butter OR Ghee OR margarine OR “dietary oil*” OR “plant oil*” OR “fish oil*” OR “olive oil*” OR “corn oil*” OR “cottonseed oil*” OR “cotton seed oil*” OR “safflower oil*” OR “sesame oil*” OR “soybean oil*” OR “soya-bean oil*” OR “linseed oil*” OR “canola oil*” OR “peanut oil*” OR “coconut oil*” OR “edible oil*” OR “palm oil*” OR “fish oil*” OR “maize oil*” OR “oleic acid*”
  - #S3 - ((fat OR fatty) N6 (saturat* OR unsatur* OR monounsatur* OR polyunsatur* OR poly-unsatur* OR “linolenic acid*” OR milk OR “infant formula*”))
  - #S4 - S1 OR S2 OR S3
  - #S5 - (MH “Cardiovascular Diseases”) OR (MH “Heart Failure+”) OR (MH “Myocardial Ischemia+”) OR (MH “Myocardial Infarction+”) OR (MH “Stroke+”) OR (MH “Cardiovascular System+”) OR (MH “Venous Thrombosis+”) OR (MH “Lipids/BL”) OR (MH “Lipoproteins, HDL Cholesterol”) OR (MH “Lipoproteins, LDL Cholesterol”) OR (MH “Triglycerides”)
  - #S6 - “cardiovascular disease*” OR “coronary artery disease” OR “heart disease*” OR “heart failure” OR “myocardial infarction*” OR “myocardial ischemia*” OR stroke OR angina OR “heart attack” OR “cardiometabolic health” OR “cardiovascular health” OR “cardiac health” OR “cardiovascular biomarkers” OR “venous thrombosis” OR hypertension OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR triglycerides
  - #S7 - S5 OR S6
  - #S8 - (MH “Child+”) OR (MH “Adolescence+”) OR (MH “Pediatrics+”) OR (MH “Infant+”)
  - #S9 - Child OR children OR youth* OR adolescence OR adolescent* OR teen OR teens OR teenager* OR preteen* OR pre-teen* OR pre-adolesc* OR preadolesc* OR preschool* OR pediatric* OR paediatric* OR Infan* OR newborn* OR new-born* OR perinat* OR neonat* OR prematur* OR preterm* OR baby OR babies OR toddler* OR boy OR boys OR girl OR girls OR schoolchild* OR “middle school*” OR “high school*” OR juvenile OR pubescent OR “pre pubescent” OR prepubescent OR kid OR kids OR “early childhood” OR “early years” OR pre-k OR pre-primary OR “under five*” OR “young child*” OR “head start” OR prekindergarten OR pre-kindergarten
  - #S10 - S8 OR S9
  - #S11 - S4 AND S7 AND S10 NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication”) Limiters - Publication Year: 1990-2009; Peer Reviewed; English Language; Human

#### Search Strategy 2: Search strategy to capture the literature on types of dietary fats and risk of cardiovascular disease for all ages from 2010-2019

##### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: October 30, 2019
- Date range searched: January 1, 2010- October 30, 2019
- Search Terms:
  - #1 - “Dietary Fats”[Mesh] OR dietary fat* OR diet fat* OR dietary lipid* OR fat consumption* OR fat intake* OR “Fatty Acids”[Mesh:noexp] OR fatty acid* OR saturated fat* OR “Fatty Acids, Monounsaturated”[Mesh] OR monounsaturated fat* OR mono-unsaturated fat* OR polyunsaturated fat* OR poly-unsaturated fat* OR unsaturated fat* OR unsaturated fatty acid* OR “Fatty Acids, Omega-3”[Mesh] OR omega-3[tiab] OR N-3 fatty acid* OR “Fatty Acids, Omega-6”[Mesh] OR omega-6 OR N-6 fatty acid* OR MUFA* OR PUFA* OR “Cholesterol, Dietary”[Mesh] OR dietary cholesterol* OR alpha-linolenic acid* OR eicosapentaenoic acid* OR docosahexaenoic acid* OR linoleic acid* OR alpha-linolenic acid* OR arachidonic acid* OR “Fats, Unsaturated”[Mesh] OR milk fat*[tiab] OR “Butter”[Mesh] OR butter[tiab] OR Ghee[tiab] OR “Margarine”[Mesh] OR margarine[tiab] OR dietary oil* OR “Plant Oils”[Mesh] OR plant oil* OR “Fish Oils”[Mesh] OR fish oil* OR olive oil* OR corn oil* OR cottonseed oil* OR cotton seed oil* OR safflower oil* OR sesame oil* OR soybean oil* OR soya-bean oil* OR linseed oil* OR canola oil* OR peanut oil* OR coconut oil* OR edible oil* OR palm oil* OR fish oil* OR maize oil* OR oleic acid* OR ((fat[tiab] OR fatty[tiab]) AND (saturat* OR unsatur* OR monounsatur* OR polyunsatur* OR poly-unsatur* OR linolenic acid* OR “Milk”[Mesh] OR milk[tiab] OR “Infant Formula”[Mesh] OR infant formula*[tiab]))
  - #2 - “Cardiovascular Diseases”[Mesh:noexp] OR cardiovascular disease*[tiab] OR coronary artery disease[tiab] OR heart disease*[tiab] OR “Heart Failure”[Mesh] OR heart failure[tiab] OR “Myocardial Infarction”[Mesh] OR myocardial infarction*[tiab] OR “Myocardial Ischemia”[Mesh] OR Myocardial Ischemia*[tiab] OR “Stroke”[Mesh] OR stroke[tiab] OR angina[tiab] OR heart attack[tiab] OR “Cardiovascular System”[Mesh] OR “cardiometabolic health” OR cardiovascular health[tiab] OR “cardiac health” OR “cardiovascular biomarkers” OR “Venous Thrombosis”[Mesh] OR venous thrombosis[tiab] OR hypertension[tiab] OR high blood pressure[tiab] OR “Lipids/blood”[Mesh] OR “Cholesterol, HDL”[Mesh] OR HDL cholesterol[tiab] OR “Cholesterol, LDL”[Mesh] OR LDL cholesterol[tiab] OR total cholesterol[tiab] OR “Triglycerides”[Mesh] OR triglycerides[tiab]
  - #3 - (#1 AND #2)
  - #4 - (#1 AND #2) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2010/01/01 to 2019/10/30; English

##### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: October 30, 2019
- Date range searched: January 1, 2010- October 30, 2019
- Search Terms:
  - #1 - [mh “Dietary Fats”] OR [mh ^“Fatty Acids”] OR [mh “Fatty Acids, Monounsaturated”] OR [mh “Fatty Acids, Omega-3”] OR [mh “Fatty Acids, Omega-6”] OR [mh “Cholesterol, Dietary”] OR [mh “Fats, Unsaturated”] OR [mh Butter] OR [mh Margarine] OR [mh “Plant Oils”] OR [mh “Fish Oils”]
  - #2 - (“dietary fat*” OR “diet fat*” OR “dietary lipid*” OR “fat consumption*” OR “fat intake*” OR “fatty acid*” OR “saturated fat*” OR “monounsaturated fat*” OR “mono-unsaturated fat*” OR “polyunsaturated fat*” OR “poly-unsaturated fat*” OR “unsaturated fat*” OR “unsaturated fatty acid*” OR omega-3 OR “N-3 fatty acid*” OR omega-6 OR “N-6 fatty acid*” OR MUFA* OR PUFA* OR “dietary cholesterol*” OR “alpha-linolenic acid*” OR “eicosapentaenoic acid*” OR “docosahexaenoic acid*” OR “linoleic acid*” OR “alpha-linolenic acid*” OR “arachidonic acid*” OR “milk fat*” OR butter OR Ghee OR margarine OR “dietary oil*” OR “plant oil*” OR “fish oil*” OR “olive oil*” OR “corn oil*” OR “cottonseed oil*” OR “cotton seed oil*” OR “safflower oil*” OR “sesame oil*” OR “soybean oil*” OR “soya-bean oil*” OR “linseed oil*” OR “canola oil*” OR “peanut oil*” OR “coconut oil*” OR “edible oil*” OR “palm oil*” OR “fish oil*” OR “maize oil*” OR “oleic acid*”):ti,ab,kw
  - #3 - ((fat OR fatty) NEAR/6 (saturat* OR unsatur* OR monounsatur* OR polyunsatur* OR poly-unsatur* OR “linolenic acid*” OR [mh Milk] OR milk OR [mh “Infant Formula”] OR “infant formula*”)):ti,ab,kw
  - #4 - #1 OR #2 OR #3
  - #5 - [mh ^“Cardiovascular Diseases”] OR [mh “Heart Failure”] OR [mh “Myocardial Ischemia”] OR [mh “Myocardial Infarction”] OR [mh Stroke] OR [mh “Cardiovascular System”] OR [mh “Venous Thrombosis”] OR [mh Lipids/BL] OR [mh “Cholesterol, HDL”] OR [mh “Cholesterol, LDL”] OR [mh Triglycerides]
  - #6 - (“cardiovascular disease*” OR “coronary artery disease” OR “heart disease*” OR “heart failure” OR “myocardial infarction*” OR “myocardial ischemia*” OR stroke OR angina OR “heart attack” OR “cardiometabolic health” OR “cardiovascular health” OR “cardiac health” OR “cardiovascular biomarkers” OR “venous thrombosis” OR hypertension OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR triglycerides):ti,ab,kw”
  - #7 - #5 OR #6
  - #8 - #4 AND #7” with Publication Year from 2010 to 2019, in Trials (Word variations have been searched)

##### Embase

- Provider: Elsevier
- Date(s) Searched: October 30, 2019
- Date range searched: January 1, 2010- October 30, 2019
- Search Terms:
  - #1 - ‘edible oil’/exp OR ‘fatty acid’/de OR ‘monounsaturated fatty acid’/de OR ‘omega 3 fatty acid’/de OR ‘omega 6 fatty acid’/de OR ‘cholesterol intake’/de OR ‘unsaturated fatty acid’/exp OR ‘butter’/de OR ‘margarine’/de OR ‘vegetable oil’/exp OR ‘fish oil’/de
  - #2 - ‘dietary fat*’:ab,ti OR ‘diet fat*’:ab,ti OR ‘dietary lipid*’:ab,ti OR ‘fat consumption*’:ab,ti OR ‘fat intake*’:ab,ti OR ‘fatty acid*’:ab,ti OR ‘saturated fat*’:ab,ti OR ‘monounsaturated fat*’:ab,ti OR ‘mono-unsaturated fat*’:ab,ti OR ‘polyunsaturated fat*’:ab,ti OR ‘poly-unsaturated fat*’:ab,ti OR ‘unsaturated fat*’:ab,ti OR ‘unsaturated fatty acid*’:ab,ti OR ‘omega 3’:ab,ti OR ‘n-3 fatty acid*’:ab,ti OR ‘omega 6’:ab,ti OR ‘n-6 fatty acid*’:ab,ti OR mufa*:ab,ti OR pufa*:ab,ti OR ‘dietary cholesterol*’:ab,ti OR ‘eicosapentaenoic acid*’:ab,ti OR ‘docosahexaenoic acid*’:ab,ti OR ‘linoleic acid*’:ab,ti OR ‘alpha-linolenic acid*’:ab,ti OR ‘arachidonic acid*’:ab,ti OR ‘milk fat*’:ab,ti OR butter:ab,ti OR ghee:ab,ti OR margarine:ab,ti OR ‘dietary oil*’:ab,ti OR ‘plant oil*’:ab,ti OR ‘olive oil*’:ab,ti OR ‘corn oil*’:ab,ti OR ‘cottonseed oil*’:ab,ti OR ‘cotton seed oil*’:ab,ti OR ‘safflower oil*’:ab,ti OR ‘sesame oil*’:ab,ti OR ‘soybean oil*’:ab,ti OR ‘soya-bean oil*’:ab,ti OR ‘linseed oil*’:ab,ti OR ‘canola oil*’:ab,ti OR ‘peanut oil*’:ab,ti OR ‘coconut oil*’:ab,ti OR ‘edible oil*’:ab,ti OR ‘palm oil*’:ab,ti OR ‘fish oil*’:ab,ti OR ‘maize oil*’:ab,ti OR ‘oleic acid*’:ab,ti
  - #3 - ((fat OR fatty) NEAR/6 (saturat* OR unsatur* OR monounsatur* OR polyunsatur* OR poly-unsatur* OR ‘linolenic acid*’ OR milk OR ‘infant formula*’)):ab,ti
  - #4 - #1 OR #2 OR #3
  - #5 - ‘cardiovascular disease’/de OR ‘heart failure’/exp OR ‘heart muscle ischemia’/exp OR ‘heart infarction’/exp OR ‘cerebrovascular accident’/exp OR ‘cardiovascular system’/exp OR ‘vein thrombosis’/exp OR ‘high density lipoprotein cholesterol’/de OR ‘low density lipoprotein cholesterol’/de OR ‘triacylglycerol’/exp
  - #6 - ‘cardiovascular disease*’:ab,ti OR ‘coronary artery disease’:ab,ti OR ‘heart disease*’:ab,ti OR ‘heart failure’:ab,ti OR ‘myocardial infarction*’:ab,ti OR ‘myocardial ischemia*’:ab,ti OR stroke:ab,ti OR angina:ab,ti OR ‘heart attack’:ab,ti OR ‘cardiometabolic health’:ab,ti OR ‘cardiovascular health’:ab,ti OR ‘cardiac health’:ab,ti OR ‘cardiovascular biomarkers’:ab,ti OR ‘venous thrombosis’:ab,ti OR hypertension:ab,ti OR ‘high blood pressure’:ab,ti OR ‘hdl cholesterol’:ab,ti OR ‘ldl cholesterol’:ab,ti OR ‘total cholesterol’:ab,ti OR triglycerides:ab,ti
  - #7 - #5 OR #6
  - #8 - #4 AND #7 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2010-2019]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

##### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) Searched: October 30, 2019
- Date range searched: January 1, 2010-December 31, 2019
- Search Terms:
  - #S1 - (MH “Dietary Fats+”) OR (MH “Fatty Acids”) OR (MH “Fatty Acids, Monounsaturated+”) OR (MH “Fatty Acids, Omega-3+”) OR (MH “Fatty Acids, Omega-6+”) OR (MH “Cholesterol, Dietary”) OR (MH “Fats, Unsaturated+”) OR (MH “Butter”) OR (MH “Margarine”) OR (MH “Plant Oils+”) OR (MH “Fish Oils+”)
  - #S2 - “dietary fat*” OR “diet fat*” OR “dietary lipid*” OR “fat consumption*” OR “fat intake*” OR “fatty acid*” OR “saturated fat*” OR “monounsaturated fat*” OR “mono-unsaturated fat*” OR “polyunsaturated fat*” OR “poly-unsaturated fat*” OR “unsaturated fat*” OR “unsaturated fatty acid*” OR omega-3 OR “N-3 fatty acid*” OR omega-6 OR “N-6 fatty acid*” OR MUFA* OR PUFA* OR “dietary cholesterol*” OR “alpha-linolenic acid*” OR “eicosapentaenoic acid*” OR “docosahexaenoic acid*” OR “linoleic acid*” OR “alpha-linolenic acid*” OR “arachidonic acid*” OR “milk fat*” OR butter OR Ghee OR margarine OR “dietary oil*” OR “plant oil*” OR “fish oil*” OR “olive oil*” OR “corn oil*” OR “cottonseed oil*” OR “cotton seed oil*” OR “safflower oil*” OR “sesame oil*” OR “soybean oil*” OR “soya-bean oil*” OR “linseed oil*” OR “canola oil*” OR “peanut oil*” OR “coconut oil*” OR “edible oil*” OR “palm oil*” OR “fish oil*” OR “maize oil*” OR “oleic acid*”
  - #S3 - ((fat OR fatty) N6 (saturat* OR unsatur* OR monounsatur* OR polyunsatur* OR poly-unsatur* OR “linolenic acid*” OR milk OR “infant formula*”))
  - #S4 - S1 OR S2 OR S3
  - #S5 - (MH “Cardiovascular Diseases”) OR (MH “Heart Failure+”) OR (MH “Myocardial Ischemia+”) OR (MH “Myocardial Infarction+”) OR (MH “Stroke+”) OR (MH “Cardiovascular System+”) OR (MH “Venous Thrombosis+”) OR (MH “Lipids/BL”) OR (MH “Lipoproteins, HDL Cholesterol”) OR (MH “Lipoproteins, LDL Cholesterol”) OR (MH “Triglycerides”)
  - #S6 - “cardiovascular disease*” OR “coronary artery disease” OR “heart disease*” OR “heart failure” OR “myocardial infarction*” OR “myocardial ischemia*” OR stroke OR angina OR “heart attack” OR “cardiometabolic health” OR “cardiovascular health” OR “cardiac health” OR “cardiovascular biomarkers” OR “venous thrombosis” OR hypertension OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR triglycerides
  - #S7 - S5 OR S6
  - #S8 - S4 AND S7 NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication”) Limiters - Publication Year: 2010-2019; Peer Reviewed; English Language; Human

## LITERATURE SEARCHES AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature searches and screening results for articles examining the systematic review question. The results of the two literature searches, after removal of duplicates, were combined for efficiency and screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 12 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature searches and screening results^*^ * The flow chart depicts the combined raw search totals from the two literature searches that included 43,989 raw results, 6,048 raw results in the first search strategy and 37,941 raw results in the second search strategy (both search strategies described in the Electronic databases and search terms section). Search results were combined for efficiency and screened together in screening software by two analysts independently because both searches addressed the same overall systematic review question from different search date ranges.

This flow chart illustrates the literature search and screening results for articles examining the relationship between types of fat consumed and risk of cardiovascular disease. The literature search yielded 43,989 articles, with 28,111 articles after duplicates were removed. During title screening, 23,285 articles were screened out. During abstract screening, 3,500 articles were screened out. During full-text screening, 1,103 articles were screened out. During the hand search, 5 additional articles were identified to include. A total of 228 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles

The table below (Table 12) lists the articles excluded after full-text screening from two literature searches, and includes columns for the categories of inclusion and exclusion criteria that studies were excluded based on. At least one reason for exclusion is provided for each article, as indicated by an “X” in one of the columns, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 12 Articles excluded after full-text screening with rationale for exclusion^*^

| Reference | Study Design | Intervention/Exposure or Comparator | Outcome | Other
1 | Aadland EK, Lavigne C, Graff IE, et al. Lean-seafood intake reduces cardiovascular lipid risk factors in healthy subjects: results from a randomized controlled trial with a crossover design. Am J Clin Nutr. 2015;102(3):582-92. doi:10.3945/ajcn.115.112086 | | X
2 | Abbott L, Gordon Schluck G, Graven L, Martorella G. Exploring the intervention effect moderators of a cardiovascular health promotion study among rural African-Americans. Public Health Nurs. 2018;35(2):126-134. doi:10.1111/phn.12377 | | X
3 | Abdullah MM, Cyr A, Lepine MC, et al. Common variants in cholesterol synthesis- and transport-related genes associate with circulating cholesterol responses to intakes of conventional dairy products in healthy individuals. J Nutr. 2016;146(5):1008-16. doi:10.3945/jn.115.222208 | | X
4 | Abellan R, Mansego ML, Martinez-Hervas S, et al. Dietary polyunsaturated fatty acids may increase plasma LDL-cholesterol and plasma cholesterol concentrations in carriers of an ABCG1 gene single nucleotide polymorphism: study in two Spanish populations. Atherosclerosis. 2011;219(2):900-6. doi:10.1016/j.atherosclerosis.2011.09.018 | X
5 | AbuMweis SS, Panchal SK, Jones PJH. Triacylglycerol-lowering effect of docosahexaenoic acid is not influenced by single-nucleotide polymorphisms involved in lipid metabolism in humans. Lipids. 2018;53(9):897-908. doi:10.1002/lipd.12096 | | X
6 | Abu-Saad K, Novikov I, Gimpelevitz I, et al. Micronutrient intake and adherence to DASH diet are associated with incident major adverse cardiovascular events and all-cause mortality in a bi-ethnic population. Eur Heart J. 2017;381120-. doi:10.1093/eurheartj/ehx502.P5321 | | | | Publication Status
7 | AbuZaid OI, Al-Dhaif BM, Alqunais FE, Ismail MS. Impact of metabolic syndrome on nutrients intakes among Saudi females. J Pak Med Assoc. 2019;69(3):330-336. | X | | X
8 | Adamsson V, Cederholm T, Vessby B, Risérus U. Influence of a healthy Nordic diet on serum fatty acid composition and associations with blood lipoproteins - results from the NORDIET study. Food Nutr Res. 2014;58. doi:10.3402/fnr.v58.24114 | | X | | Health Status
9 | Adamsson V, Reumark A, Fredriksson IB, et al. Effects of a healthy Nordic diet on cardiovascular risk factors in hypercholesterolaemic subjects: a randomized controlled trial (NORDIET). J Intern Med. 2011;269(2):150-9. doi:10.1111/j.1365-2796.2010.02290.x | | X
10 | Adedeji OO, Oyakhire GK, Saeed AK, Ghamdi AI. Effectiveness of interventions to reduce coronary heart disease risk. West Afr J Med. 2011;30(3):197-201. | X | X
11 | Adeyanju M. Adolescent health status behaviors and cardiovascular disease. Adolescence. 1990. 25(97):155-69. | | X
12 | Aeberli I, Spinas GA, Lehmann R, l’Allemand D, Molinari L, Zimmermann MB. Diet determines features of the metabolic syndrome in 6- to 14-year-old children. Int J Vitam Nutr Res. 2009. 79(1):14-23. doi:10.1024/0300-9831.79.1.14 | X
13 | Afonso C, Bernardo I, Bandarra NM, Martins LL, Cardoso C. The implications of following dietary advice regarding fish consumption frequency and meal size for the benefit (EPA + DHA and Se) versus risk (MeHg) assessment. Int J Food Sci Nutr. 2019;70(5):623-637. doi:10.1080/09637486.2018.1551334 | X | X
14 | Afshin A, Micha R, Khatibzadeh S, et al. The impact of dietary habits and metabolic risk factors on cardiovascular and diabetes mortality in countries of the Middle East and North Africa in 2010: a comparative risk assessment analysis. BMJ Open. 2015;5(5):e006385. doi:10.1136/bmjopen-2014-006385 | X
15 | Akbaraly T, Wurtz P, Singh-Manoux A, et al. Association of circulating metabolites with healthy diet and risk of cardiovascular disease: analysis of two cohort studies. Sci Rep. 2018;8(1):8620. doi:10.1038/s41598-018-26441-1 | X | X
16 | Akerblom HK, Viikari J, Raitakari OT, Uhari M. Cardiovascular Risk in Young Finns Study: general outline and recent developments. Ann Med. 1999. 31(Supp1):45-54. doi:10.1080/07853890.1999.11904399 | X
17 | Al Jamal AR, Ibrahim A. Effects of olive oil on lipid profiles and blood glucose in type2 diabetic patients. International Journal of Diabetes and Metabolism. 2011;19(1):19-22. | X
18 | Al Wattar B H, Dodds J, Placzek A, et al. Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): a pragmatic multicentre randomised trial. PLoS Med. 2019;16(7):e1002857. doi:10.1371/journal.pmed.1002857 | | X | X
19 | Albani V, Celis-Morales C, O’Donovan CB, et al. Within-person reproducibility and sensitivity to dietary change of C15:0 and C17:0 levels in dried blood spots: data from the European Food4Me Study. Mol Nutr Food Res. 2017;61(10). doi:10.1002/mnfr.201700142 | | | X
20 | Alexander H, Lockwood LP, Harris MA, Melby CL. Risk factors for cardiovascular disease and diabetes in two groups of Hispanic Americans with differing dietary habits. J Am Coll Nutr. 1999. 18(2):127-36. doi:10.1080/07315724.1999.10718840 | X
21 | Alfaddagh A, Elajami TK, Ashfaque H, Saleh M, Bistrian BR, Welty FK. Effect of eicosapentaenoic and docosahexaenoic acids added to statin therapy on coronary artery plaque in patients with coronary artery disease: a randomized clinical trial. J Am Heart Assoc. 2017;6(12): pii: e006981. doi:10.1161/jaha.117.006981 | | X | | Health Status
22 | Al-Ghannami SS, Sedlak E, Hussein IS, et al. Lipid-soluble nutrient status of healthy Omani school children before and after intervention with oily fish meal or re-esterified triacylglycerol fish oil. Nutrition. 2016;32(1):73-8. doi:10.1016/j.nut.2015.07.014 | | X | X
23 | Alipoor B, Haghighian MK, Sadat BE, Asghari M. Effect of sesame seed on lipid profile and redox status in hyperlipidemic patients. Int J Food Sci Nutr. 2012;63(6):674-8. doi:10.3109/09637486.2011.652077 | | | | Health Status
24 | Aljohi H, Dopler-Nelson M, Cifuentes M, Wilson TA. The consumption of 12 Eggs per week for 1year does not alter fasting serum markers of cardiovascular disease in older adults with early macular degeneration. J Nutr Intermed Metabol. 2019;15:35-41. doi:10.1016/j.jnim.2018.11.004 | | X
25 | Aller R, de Luis DA, Izaola O, de la Fuente B, Bachiller R. Effect of a high monounsaturated vs high polyunsaturated fat hypocaloric diets in nonalcoholic fatty liver disease. Eur Rev Med Pharmacol Sci. 2014;18(7):1041-7. | | X
26 | Aller R, Primo D, Izaola O, de Luis DA. Common polymorphism in the cannabinoid receptor gene type 2 (CB2R) rs3123554 are associated with metabolic changes after two different hypocaloric diets with different dietary fatty profiles. Clin Nutr. 2018. 38(6):2632-2638. doi:10.1016/j.clnu.2018.11.013 | | X
27 | Allison MA, Aragaki A, Eaton C, et al. Effect of dietary modification on incident carotid artery disease in postmenopausal women: results from the women’s health initiative dietary modification trial. Stroke. 2014;45(6):1748-56. doi:10.1161/strokeaha.114.005096 | | X
28 | Allison MA, Aragaki A, Eaton C, et al. Dietary intervention to reduce fat intake does not result in lower incident carotid artery disease: the women’s health initiative diet modification trial. Circulation. 2013;128(S22): A10374 | | | | Publication Status
29 | Alonso A, Zozaya C, Vazquez Z, Alfredo Martinez J, Martinez-Gonzalez MA. The effect of low-fat versus whole-fat dairy product intake on blood pressure and weight in young normotensive adults. J Hum Nutr Diet. 2009. 22(4):336-42. doi:10.1111/j.1365-277X.2009.00967.x | | X
30 | Al-Rewashdeh AYA. Blood lipid profileoxidation and pressure of men and women consumed olive oil. Pak J Nutr. 2010;9(1):15-26. | | X
31 | Alsaleh A, Frost GS, Griffin BA, et al. PPARgamma2 gene Pro12Ala and PPARalpha gene Leu162Val single nucleotide polymorphisms interact with dietary intake of fat in determination of plasma lipid concentrations. J Nutrigenet Nutrigenomics. 2011;4(6):354-66. doi:10.1159/000336362 | | X
32 | Alsumari SR, AlNouri DM, El-Sayed MMA, El-Din MFS, Arzoo S. The sociodemographic characteristics and dietary and blood plasma fatty acid profiles of elderly Saudi women with Alzheimer disease. Lipids Health Dis. 2019;18(1):77. doi:10.1186/s12944-019-1029-0 | X | | | Health Status
33 | Alvarez Campano CG, Macleod MJ, Aucott L, Thies F. Marinederived n-3 fatty acids therapy for stroke. Stroke. 2019;50(11):e314-e315. doi:10.1161/strokeaha.119.026919 | X
34 | Alvarez-Alvarez I, Zazpe I, Pérez de Rojas J, et al. Mediterranean dietphysical activity and their combined effect on all-cause mortality: The Seguimiento Universidad de Navarra (SUN) cohort. Prev Med. 2018;106:45-52. doi:10.1016/j.ypmed.2017.09.021 | | | X
35 | Alvarez-Perez J, Sanchez-Villegas A, Diaz-Benitez EM, et al. Influence of a Mediterranean dietary pattern on body fat distribution: results of the PREDIMED-Canarias Intervention Randomized Trial. J Am Coll Nutr. 2016;35(6):568-580. doi:10.1080/07315724.2015.1102102 | | | X | Health Status
36 | Alvizouri-Munoz M, Carranza-Madrigal J, Herrera-Abarca JE, Chavez-Carbajal F, Amezcua-Gastelum JL. Effects of avocado as a source of monounsaturated fatty acids on plasma lipid levels. Arch Med Res. 1992. 23(4):163-7. | | | | Country
37 | Amba V, Murphy G, Etemadi A, Wang S, Abnet CC, Hashemian M. Nut and peanut butter consumption and mortality in the National Institutes of Health-AARP Diet and Health Study. Nutrients. 2019;11(7): pii: E1508. doi:10.3390/nu11071508 | | X | X
38 | Amundsen AL, Ose L, Nenseter MS, Ntanios FY. Plant sterol ester-enriched spread lowers plasma total and LDL cholesterol in children with familial hypercholesterolemia. Am J Clin Nutr. 2002;76(2):338-344. | | X
39 | Andersen CJ, Lee JY, Blesso CN, Carr TP, Fernandez ML. Egg intake during carbohydrate restriction alters peripheral blood mononuclear cell inflammation and cholesterol homeostasis in metabolic syndrome. Nutrients. 2014;6(7):2650-67. doi:10.3390/nu6072650 | | X | X
40 | Anderson AD, Anderson MM, Jacobson JL, et al. Metabolic effects of bedtime pistachio consumption for 6 weeks in overweight persons. FASEB journal. 2013;27. | | | | Publication Status
41 | Anderson-Vasquez HE, Perez-Martinez P, Ortega Fernandez P, Wanden-Berghe C. Impact of the consumption of a rich diet in butter and it replacement for a rich diet in extra virgin olive oil on anthropometric, metabolic and lipid profile in postmenopausal women. Nutr Hosp. 2015;31(6):2561-70. doi:10.3305/nh.2015.31.6.8732 | | | X | Study Duration
42 | Andraski AB, Singh SA, Lee L, et al. A diet high in carbohydrate and low in fat alters the HDL proteome and metabolism of 9 HDL proteins in humans. Circulation. 2019;139(Suppl 1): AMP41. doi:10.1161/circ.139.suppl_1.MP41 | | | | Publication Status
43 | Annuzzi G, Rivellese AA, Wang H, et al. Lipoprotein subfractions and dietary intake of n-3 fatty acid: the Genetics of Coronary Artery Disease in Alaska Natives study. Am J Clin Nutr. 2012;95(6):1315-22. doi:10.3945/ajcn.111.023887 | X
44 | Arora RC, Agarwal N, Arora S, Garg RK, Kumar N, Lakhtakia S. A comparative study of three different test diets in change in plasma total cholesterol in young healthy individuals. Mater Med Pol. 1991. 23(4):296-8. | X
45 | Arora RC, Agarwal N, Arora S, Pandey A. Dietary cholesterol induced changes in serum lipoproteins in healthy females. Mater Med Pol. 1992. 24(1):17-9. | | | | Age of participants at intervention or exposure
46 | Asadi Z, Shafiee M, Sadabadi F, et al. Association of dietary patterns and risk of cardiovascular disease events in the MASHAD cohort study. J Hum Nutr Diet. 2019;32(6):789-801. doi:10.1111/jhn.12669 | | X
47 | Asemi Z, Samimi M, Tabassi Z, Shakeri H, Sabihi SS, Esmaillzadeh A. Effects of DASH diet on lipid profiles and biomarkers of oxidative stress in overweight and obese women with polycystic ovary syndrome: a randomized clinical trial. Nutrition. 2014;30(11-12):1287-93. doi:10.1016/j.nut.2014.03.008 | | X
48 | Asghari G, Yuzbashian E, Mirmiran P, Bahadoran Z, Azizi F. Prediction of metabolic syndrome by a high intake of energy-dense nutrient-poor snacks in Iranian children and adolescents. Pediatr Res. 2016;79(5):697-704. doi:10.1038/pr.2015.270 | | X
49 | Ashaye A, Gaziano J, Djousse L. Red meat consumption and risk of heart failure in male physicians. Nutr Metab Cardiovasc Dis. 2011;21(12):941-6. doi:10.1016/j.numecd.2010.03.009 | | X
50 | Aslibekyan S, Campos H, Baylin A. Biomarkers of dairy intake and the risk of heart disease. Nutr Metab Cardiovasc Dis. 2012;22(12):1039-45. doi:10.1016/j.numecd.2011.02.003 | X | X
51 | Assaf-Balut C, Garcia de la Torre N, Duran A, et al. A Mediterranean diet with additional extra virgin olive oil and pistachios reduces the incidence of gestational diabetes mellitus (GDM): a randomized controlled trial: The St. Carlos GDM prevention study. PLoS One. 2017;12(10):e0185873. doi:10.1371/journal.pone.0185873 | | X | X
52 | Assaf-Balut C, Garcia de la Torre N, Duran A, et al. A Mediterranean diet with an enhanced consumption of extra virgin olive oil and pistachios improves pregnancy outcomes in women without gestational diabetes mellitus: a sub-analysis of the St. Carlos Gestational Diabetes Mellitus Prevention Study. Ann Nutr Metab. 2019;74(1):69-79. doi:10.1159/000495793 | | X | X
53 | Astrup A. Yogurt and dairy product consumption to prevent cardiometabolic diseases: epidemiologic and experimental studies. Am J Clin Nutr. 2014;99(Suppl 5):1235S-1242S. doi:10.3945/ajcn.113.073015 | X
54 | Atkins JL, Whincup PH, Morris RW, Lennon LT, Papacosta O, Wannamethee SG. Dietary patterns and the risk of CVD and all-cause mortality in older British men. Br J Nutr. 2016;116(7):1246-1255. doi:10.1017/s0007114516003147 | | X
55 | Austel A, Ranke C, Wagner N, Gorge J, Ellrott T. Weight loss with a modified Mediterranean-type diet using fat modification: a randomized controlled trial. Eur J Clin Nutr. 2015;69(8):878-84. doi:10.1038/ejcn.2015.11 | | X
56 | Avelino AP, Oliveira GM, Ferreira CC, Luiz RR, Rosa G. Additive effect of linseed oil supplementation on the lipid profiles of older adults. Clin Interv Aging. 2015;10:1679-85. doi:10.2147/cia.S75538 | | X
57 | Ayer JG, Harmer JA, Xuan W, et al. Dietary supplementation with n-3 polyunsaturated fatty acids in early childhood: effects on blood pressure and arterial structure and function at age 8 y. Am J Clin Nutr. 2009. 90(2):438-46. doi:10.3945/ajcn.2009.27811 | | X
58 | Aynaci G, Akdemir O. The relationship between lifestyle, health promotion lifestyle profile II and high blood pressure in university students. Open Access Maced J Med Sci. 2018;6(9):1756-1761. doi:10.3889/oamjms.2018.314 | X
59 | Azadbakht L, Izadi V, Ehsani S, Esmaillzadeh A. Effects of the Dietary Approaches to Stop Hypertension (DASH) eating plan on the metabolic side effects of corticosteroid medications. J Am Coll Nutr. 2016;35(4):285-90. doi:10.1080/07315724.2014.991459 | | X | | Health Status
60 | Azadbakht L, Mirmiran P, Hedayati M, Esmaillzadeh A, Shiva N, Azizi F. Particle size of LDL is affected by the National Cholesterol Education Program (NCEP) step II diet in dyslipidaemic adolescents. Br J Nutr. 2007. 98(1):134-9. doi:10.1017/s0007114507657857 | | | | Country
61 | Azadi-Yazdi M, Karimi-Zarchi M, Salehi-Abargouei A, Fallahzadeh H, Nadjarzadeh A. Effects of Dietary Approach to Stop Hypertension diet on androgens, antioxidant status and body composition in overweight and obese women with polycystic ovary syndrome: a randomised controlled trial. J Hum Nutr Diet. 2017;30(3):275-283. doi:10.1111/jhn.12433 | | X
62 | Babio N, Becerra-Tomas N, Martinez-Gonzalez MA, et al. Consumption of yogurt, low-fat milk, and other low-fat dairy products is associated with lower risk of metabolic syndrome incidence in an elderly Mediterranean population. J Nutr. 2015;145(10):2308-16. doi:10.3945/jn.115.214593 | | X
63 | Babio N, Toledo E, Estruch R, et al. Mediterranean diets and metabolic syndrome status in the PREDIMED randomized trial. CMAJ. 2014;186(17):E649-57. doi:10.1503/cmaj.140764 | | X
64 | Baer DJ, Henderson T, Gebauer SK. High oleic soybean oil improves cardiometabolic health in adults. FASEB journal. 2017;31(Suppl 1) | | | | Publication Status
65 | Bagge CN, Strandhave C, Skov CM, Svensson M, Schmidt EB, Christensen JH. Marine n-3 polyunsaturated fatty acids affect the blood pressure control in patients with newly diagnosed hypertension - a 1-year follow-up study. Nutr Res. 2017;38:71-78. doi:10.1016/j.nutres.2017.02.009 | | | | Health Status
66 | Baik I, Abbott RD, Curb JD, Shin C. Intake of fish and n-3 fatty acids and future risk of metabolic syndrome. J Am Diet Assoc. 2010;110(7):1018-26. doi:10.1016/j.jada.2010.04.013 | | | X
67 | Baila-Rueda L, Mateo-Gallego R, Perez-Calahorra S, et al. Effect of different fat-enriched meats on non-cholesterol sterols and oxysterols as markers of cholesterol metabolism: results of a randomized and cross-over clinical trial. Nutr Metab Cardiovasc Dis. 2015;25(9):853-9. doi:10.1016/j.numecd.2015.06.008 | | X | | Study Duration
68 | Balk E, Chung M, Lichtenstein A, et al. Effects of omega-3 fatty acids on cardiovascular risk factors and intermediate markers of cardiovascular disease. Evid Rep Technol Assess (Summ). 2004. (93):1- 6. | X | | | Publication Status
69 | Ballesteros MN, Cabrera RM, Del Socorro Saucedo M, Aggarwal D, Shachter NS, Fernandez ML. High intake of saturated fat and early occurence of specific biomarkers may explain the prevalence of chronic disease in northern Mexico. J Nutr. 2005. 135(1):70-73. | | | | Publication Status
70 | Bamberger C, Rossmeier A, Lechner K, et al. A walnut-enriched diet reduces lipids in healthy caucasian subjects independent of recommended macronutrient replacement and time point of consumption: a prospective randomized controlled trial. Nutrients. 2017;9(10): pii: E1097. doi:10.3390/nu9101097 | | X
71 | Barbour JA, Howe PRC, Buckley JD, Bryan J, Coates AM. Cerebrovascular and cognitive benefits of high-oleic peanut consumption in healthy overweight middle-aged adults. Nutr Neurosci. 2017;20(10):555-562. doi:10.1080/1028415x.2016.1204744 | | X | X
72 | Baril-Gravel L, Labonte ME, Couture P, et al. Docosahexaenoic acid-enriched canola oil increases adiponectin concentrations: a randomized crossover controlled intervention trial. Nutr Metab Cardiovasc Dis. 2015;25(1):52-9. doi:10.1016/j.numecd.2014.08.003 | | | X
73 | Barrubes L, Babio N, Mena-Sanchez G, et al. Dairy product consumption and risk of colorectal cancer in an older Mediterranean population at high cardiovascular risk. Int J Cancer. 2018;143(6):1356-1366. doi:10.1002/ijc.31540 | | | X
74 | Bas M, Altan T, Dincer D, Aran E, Kaya HG, Yuksek O. Determination of dietary habits as a risk factor of cardiovascular heart disease in Turkish adolescents. Eur J Nutr. 2005. 44(3):174-82. doi:10.1007/s00394-004-0509-8 | X | | X
75 | Bass JA, Moore TA, Stewart KJ. Coronary heart disease risk factors in children and adolescents. Preventive Cardiology. 1999. 2(1):8-12+22. | X
76 | Baumgartner S, Kelly ER, van der Made S, et al. The influence of consuming an egg or an egg-yolk buttermilk drink for 12 wk on serum lipids, inflammationand liver function markers in human volunteers. Nutrition. 2013;29(10):1237-44. doi:10.1016/j.nut.2013.03.020 | | X
77 | Bazzano LA, Reynolds K, Hu T, et al. Effect of a low-carbohydrate diet on weight and cardiovascular risk factors: a randomized controlled trial. Circulation. 2012;125(10): AP306 | | | | Publication Status
78 | Bekkouche L, Ait Yahia D. P1-01: Linseed consumption associated with mediterranean diet reduces hyperglycemia and blood pressure among west algerian patients with metabolic syndrome. Ann Cardiol Angeiol. 2015;64S23. doi:10.1016/S0003-3928(16)30048-8 | | | | Publication Status
79 | Bekkouche L, Bouchenak M, Malaisse WJ, Yahia DA. The Mediterranean diet adoption improves metabolicoxidativeand inflammatory abnormalities in algerian metabolic syndrome patients. Hormone and Metabolic Research. 2014;46(4):274-282. doi:10.1055/s-0033-1363657 | | X
80 | Benaim C, Freitas-Vilela AA, Pinto TJP, et al. Early pregnancy body mass index modifies the association of pre-pregnancy dietary patterns with serum polyunsaturated fatty acid concentrations throughout pregnancy in Brazilian women. Matern Child Nutr. 2018;14(1): doi:10.1111/mcn.12480 | | | X
81 | Benatar JR, Jones E, White H, Stewart RA. A randomized trial evaluating the effects of change in dairy food consumption on cardio-metabolic risk factors. Eur J Prev Cardiol. 2014;21(11):1376-86. doi:10.1177/2047487313493567 | | X
82 | Bendsen NT, Chabanova E, Thomsen HS, et al. Effect of trans fatty acid intake on abdominal and liver fat deposition and blood lipids: a randomized trial in overweight postmenopausal women. Nutr Diabetes. 2011;1e4. doi:10.1038/nutd.2010.4 | | X
83 | Bento AP, Cominetti C, Simoes Filho A, Naves MM. Baru almond improves lipid profile in mildly hypercholesterolemic subjects: a randomized, controlled crossover study. Nutr Metab Cardiovasc Dis. 2014;24(12):1330-6. doi:10.1016/j.numecd.2014.07.002 | | X | | Health Status
84 | Berard E, Bongard V, Haas B, et al. Score of adherence to 2016 European cardiovascular prevention guidelines is an independent determinant of cardiovascular and all-cause mortality in a French general population. Eur Heart J. 2017;381064. doi:10.1093/eurheartj/ehx502.P5139 | | | | Publication Status
85 | Berge K, Musa-Veloso K, Harwood M, Hoem N, Burri L. Krill oil supplementation lowers serum triglycerides without increasing low-density lipoprotein cholesterol in adults with borderline high or high triglyceride levels. Nutr Res. 2014;34(2):126-33. doi:10.1016/j.nutres.2013.12.003 | | X
86 | Berglund L, Oliver EH, Fontanez N, et al. HDL-subpopulation patterns in response to reductions in dietary total and saturated fat intakes in healthy subjects. Am J Clin Nutr. 1999. 70(6):992-1000. doi:10.1093/ajcn/70.6.992 | | | | Age of participants at intervention or exposure
87 | Bermejo LM, Rodriguez-Duran D, Lopez-Plaza B, et al. Effects of a functional light cheese naturally enriched with CLA and omega-3 improving blood lipid profile in overweight and obese people treatment. Clinical nutrition supplement. 2012;7(1):219. doi:10.1016/S1744-1161(12)70543-4 | | | | Publication Status
88 | Bernic D, Brassard D, Droit A, et al. Comparing the impact of saturated fatty acids from different dairy sources on the proteome of high density lipoproteins. FASEB journal. 2017;31(Suppl 1): lb272-lb272 | | | | Publication Status
89 | Bernic D, Brassard D, Tessier-Grenier M, et al. Comparing the impact of saturated fatty acids from different dairy sources on LDL particle size phenotype. FASEB journal. 2017;31(Suppl 1): 966-5 | | | | Publication Status
90 | Berryman CE, Fleming JA, Kris-Etherton PM. Inclusion of almonds in a cholesterol-lowering diet improves plasma HDL subspecies and cholesterol efflux to serum in normal-weight individuals with elevated LDL cholesterol. J Nutr. 2017;147(8):1517-1523. doi:10.3945/jn.116.245126 | | | | Health Status
91 | Berryman CE, West SG, Fleming JA, Bordi PL, Kris-Etherton PM. Effects of daily almond consumption on cardiometabolic risk and abdominal adiposity in healthy adults with elevated LDL-cholesterol: a randomized controlled trial. J Am Heart Assoc. 2015;4(1):e000993. doi:10.1161/jaha.114.000993 | | X | | Health Status
92 | Beydoun MA, Fanelli-Kuczmarski MT, Beydoun HA, et al. Dairy product consumption and its association with metabolic disturbance in a prospective study of urban adults. Br J Nutr. 2018;119(6):706-719. doi:10.1017/s0007114518000028 | | X
93 | Bhardwaj R, Dod H, Sandhu MS, et al. Acute effects of diets rich in almonds and walnuts on endothelial function. Indian Heart J. 2018;70(4):497-501. doi:10.1016/j.ihj.2018.01.030 | | | | Study Duration
94 | Bhatt SP, Misra A, Nigam P. Nutrition and physical activity in Asian Indians with non-alcoholic fatty liver: a case control study. Diabetes Metab Syndr. 2019;13(2):1271-1274. doi:10.1016/j.dsx.2019.01.054 | X | | | Country
95 | Bian S, Gao Y, Zhang M, et al. Dietary nutrient intake and metabolic syndrome risk in Chinese adults: a case-control study. Nutr J. 2013;12(1):106. doi:10.1186/1475-2891-12-106 | X | X
96 | Bigornia SJ, Scott TM, Harris WS, Tucker KL. Prospective associations of erythrocyte composition and dietary intake of n-3 and n-6 PUFA with measures of cognitive function. Nutrients. 2018;10(9):1253. doi:10.3390/nu10091253 | | | X
97 | Bihuniak JD, Ramos A, Huedo-Medina T, Hutchins-Wiese H, Kerstetter JE, Kenny AM. Adherence to a Mediterranean-Style Diet and Its Influence on Cardiovascular Risk Factors in Postmenopausal Women. J Acad Nutr Diet. 2016;116(11):1767-1775. doi:10.1016/j.jand.2016.06.377 | | X
98 | Bjerregaard P, Pedersen HS, Mulvad G. The associations of a marine diet with plasma lipids blood glucose blood pressure and obesity among the Inuit in Greenland. Eur J Clin Nutr. 2000. 54(9):732-7. doi: 10.1038/sj.ejcn.1601088 | | X | | Age of participants at intervention or exposure
99 | Bjerregaard P. The association of n-3 fatty acids with serum High Density Cholesterol (HDL) is modulated by sex but not by Inuit ancestry. Atherosclerosis. 2013;226(1):281-5. doi:10.1016/j.atherosclerosis.2012.10.071 | X | X
100 | Bjerve KS, Thoresen L, Bonaa K, Vik T, Johnsen H, Brubakk AM. Clinical studies with alpha-linolenic acid and long-chain n-3 fatty acids. Nutrition. 1992. 8(2):130-2. | | | X | Health Status
101 | Bjornshave A, Holst JJ, Hermansen K. A pre-meal of whey proteins induces differential effects on glucose and lipid metabolism in subjects with the metabolic syndrome: a randomised cross-over trial. Eur J Nutr. 2019;58(2):755-764. doi:10.1007/s00394-018-1684-3 | | X | X
102 | Blesso CN, Andersen CJ, Barona J, Volk B, Volek JS, Fernandez ML. Effects of carbohydrate restriction and dietary cholesterol provided by eggs on clinical risk factors in metabolic syndrome. J Clin Lipidol. 2013;7(5):463-71. doi:10.1016/j.jacl.2013.03.008 | | | | Duplicate
103 | Blom WAM, Koppenol WP, Hiemstra H, Stojakovic T, Scharnagl H, Trautwein EA. A low-fat spread with added plant sterols and fish omega-3 fatty acids lowers serum triglyceride and LDL-cholesterol concentrations in individuals with modest hypercholesterolaemia and hypertriglyceridaemia. Eur J Nutr. 2019;58(4):1615-1624. doi:10.1007/s00394-018-1706-1 | | X | | Health Status
104 | Bobes J, Arango C, Garcia-Garcia M, Rejas J. Healthy lifestyle habits and 10-year cardiovascular risk in schizophrenia spectrum disorders: an analysis of the impact of smoking tobacco in the CLAMORS schizophrenia cohort. Schizophr Res. 2010;119(1-3):101-9. doi:10.1016/j.schres.2010.02.1030 | X | | | Health Status
105 | Bodhini D, Gaal S, Shatwan I, et al. Interaction between TCF7L2 polymorphism and dietary fat intake on high density lipoprotein cholesterol. PLoS One. 2017;12(11):e0188382. doi:10.1371/journal.pone.0188382 | X | | | Country
106 | Bogl LH, Maranghi M, Rissanen A, Kaprio J, Taskinen MR, Pietilainen KH. Dietary omega-3 polyunsaturated fatty acid intake is related to a protective high-density lipoprotein subspecies profile independent of genetic effects: a monozygotic twin pair study. Atherosclerosis. 2011;219(2):880-6. doi:10.1016/j.atherosclerosis.2011.09.010 | X
107 | Bohl M, Bjornshave A, Larsen MK, Gregersen S, Hermansen K. Effects of medium-chain saturated dairy fat on the body composition of abdominal obese subjects (DairyHealth): a 12weekrandomiseddouble-blindedintervention study. Diabetologia. 2015;58(S1):S335- S336. doi:10.1007/s00125-015-3687-4 | | | | Publication Status
108 | Bonaccio M, Di Castelnuovo A, Pounis G, et al. High adherence to the Mediterranean diet is associated with cardiovascular protection in higher but not in lower socioeconomic groups: prospective findings from the Moli-sani study. Int J Epidemiol. 2017;46(5):1478-1487. doi:10.1093/ije/dyx145 | | X
109 | Bonaccio M, Ruggiero E, Di Castelnuovo A, et al. Fish intake is associated with lower cardiovascular risk in a Mediterranean population: prospective results from the Moli-sani study. Nutr Metab Cardiovasc Dis. 2017;27(10):865-873. doi:10.1016/j.numecd.2017.08.004 | | X
110 | Bonafini S, Tagetti A, Gaudino R, et al. Individual fatty acids in erythrocyte membranes are associated with several features of the metabolic syndrome in obese children. Eur J Nutr. 2019;58(2):731-742. doi:10.1007/s00394-018-1677-2 | X
111 | Bondia-Pons I, Poho P, Bozzetto L, et al. Isoenergetic diets differing in their n-3 fatty acid and polyphenol content reflect different plasma and HDL-fraction lipidomic profiles in subjects at high cardiovascular risk. Mol Nutr Food Res. 2014;58(9):1873-82. doi:10.1002/mnfr.201400155 | | | | Duplicate data
112 | Bonet Serra B, Quintanar Rioja A, Viana Arribas M, Iglesias-Gutierrez E, Varela-Moreiras G. The effects of yogurt with isomer enriched conjugated linoleic acid on insulin resistance in obese adolescents. Rev Esp Pediatr. 2008. 64(1):94- 100. | | | | Language
113 | Bonthuis M, Hughes MC, Ibiebele TI, Green AC, van der Pols JC. Dairy consumption and patterns of mortality of Australian adults. Eur J Clin Nutr. 2010;64(6):569-77. doi:10.1038/ejcn.2010.45 | | X
114 | Bosaeus M, Hussain A, Karlsson T, et al. A randomized longitudinal dietary intervention study during pregnancy: effects on fish intakephospholipidsand body composition. Nutr J. 2015;141. doi:10.1186/1475-2891-14-1 | | X | X
115 | Bouchard-Mercier A, Godin G, Lamarche B, Perusse L, Vohl MC. Effects of peroxisome proliferator-activated receptorsdietary fat intakes and gene-diet interactions on peak particle diameters of low-density lipoproteins. J Nutrigenet Nutrigenomics. 2011;4(1):36-48. doi:10.1159/000324531 | X | | X
116 | Bouillon K, Singh-Manoux A, Jokela M, et al. Decline in low-density lipoprotein cholesterol concentration: lipid-lowering drugsdietor physical activity? Evidence from the Whitehall II study. Heart. 2011;97(11):923-30. doi:10.1136/hrt.2010.216309 | | X | X
117 | Boulton TJ, Magarey AM, Cockington RA. Tracking of serum lipids and dietary energy, fat and calcium intake from 1 to 15 years. Acta Paediatr. 1995. 84(9):1050-5. doi:10.1111/j.1651-2227.1995.tb13823.x | | X
118 | Bouziotas C, Koutedakis Y, Nevill A, et al. Greek adolescents, fitness, fatness, fat intake, activity, and coronary heart disease risk. Arch Dis Child. 2004. 89(1):41-4. | X
119 | Bouziotas C, Koutedakis Y. A three year study of coronary heart disease risk factors in Greek adolescents. Pediatric Exercise Science. 2003. 15(1):9-18. doi:10.1123/pes.15.1.9 | X | X
120 | Bowen J, Brindal E, James-Martin G, Noakes M. Randomized trial of a high protein, partial meal replacement program with or without alternate day fasting: Similar effects on weight loss, retention status, nutritional, metabolic, and behavioral outcomes. Nutrients. 2018;10(9): pii: E1145. doi:10.3390/nu10091145 | | X
121 | Bowen KJ, Kris-Etherton PM, Jones PJ, Reddivari L. Effects of diets that vary in fatty acid composition on fecal short-chain fatty acid levels and their relationship with circulating lipids and lipoproteins. Circulation. 2019;139(Suppl 1): AP293. doi:10.1161/circ.139.suppl_1.P293 | | | | Publication Status
122 | Bowen KJ, Kris-Etherton PM, West SG, et al. Canola and high-oleic acid canola oils improve lipid/lipoprotein parameters compared to an oil blend characteristic of a western dietary pattern in individuals at risk for metabolic syndrome: a randomized crossover clinical trial. Circulation. 2018;137(Suppl 1): AP382 | | | | Publication Status
123 | Bozza R, Campos WD, Barbosa Filho VC, Stabelini Neto A, Silva MP, Maziero RS. High blood pressure in adolescents of Curitiba: Prevalence and associated factors. Arq Bras Cardiol. 2016;106(5):411-8. doi:10.5935/abc.20160044 | X
124 | Bozzetto L, Annuzzi G, Pacini G, et al. Polyphenol-rich diets improve glucose metabolism in people at high cardiometabolic risk: a controlled randomised intervention trial. Diabetologia. 2015;58(7):1551-60. doi:10.1007/s00125-015-3592-x | | | X
125 | Brahe LK, Angquist L, Larsen LH, et al. Influence of SNPs in nutrient-sensitive candidate genes and gene-diet interactions on blood lipids: the DiOGenes study. Br J Nutr. 2013;110(5):790-6. doi:10.1017/s0007114512006058 | | X
126 | Brassard D, Arsenault B, Boyer M, et al. Effects of saturated fatty acids from butter and cheese on high-density lipoprotein (HDL)-mediated cholesterol efflux capacity. FASEB journal. 2017;Conference: Experimental Biology 2017, EB. United States. 31(Suppl 1):146 | | | | Publication Status
127 | Brassard D, Arsenault BJ, Boyer M, et al. Saturated fats from butter but not from cheese increase HDL-mediated cholesterol efflux capacity from J774 macrophages in men and women with abdominal obesity. J Nutr. 2018;148(4):573-580. doi:10.1093/jn/nxy014 | | | | Duplicate data
128 | Bray GA, Redman LM, de Jonge L, Rood J, Sutton EF, Smith SR. Plasma fatty acyl-carnitines during 8weeks of overfeeding: relation to diet energy expenditure and body composition: the PROOF study. Metabolism. 2018;831-10. doi:10.1016/j.metabol.2018.01.019 | | X | X
129 | Brox J, Bjornstad E, Olaussen K, Osterud B, Almdahl S, Lochen ML. Blood lipids, fatty acids, diet and lifestyle parameters in adolescents from a region in northern Norway with a high mortality from coronary heart disease. Eur J Clin Nutr. 2002;56(7):694-700. doi:10.1038/sj.ejcn.1601381 | | X
130 | Bruce B, Spiller GA, Klevay LM, Gallagher SK. A diet high in whole and unrefined foods favorably alters lipids, antioxidant defenses, and colon function. J Am Coll Nutr. 2000. 19(1):61-7. doi:10.1080/07315724.2000.10718915 | | X
131 | Bruno R, Petrella E, Bertarini V, Pedrielli G, Neri I, Facchinetti F. Adherence to a lifestyle programme in overweight/obese pregnant women and effect on gestational diabetes mellitus: a randomized controlled trial. Matern Child Nutr. 2017;13(3): e12333. doi:10.1111/mcn.12333 | | X
132 | Bruun S, van Rossem L, Lauritzen L, et al. Content of n-3 LC-PUFA in breast milk four months postpartum is associated with infancy blood pressure in boys and infancy blood lipid profile in girls. Nutrients. 2019;11(2): 235. doi:10.3390/nu11020235 | | X
133 | Bub A, Malpuech-Brugere C, Orfila C, et al. A Dietary Intervention of Bioactive Enriched Foods Aimed at Adults at Risk of Metabolic Syndrome: Protocol and Results from PATHWAY-27 Pilot Study. Nutrients. 2019;11(8): 1814. doi:10.3390/nu11081814 | | X
134 | Buckland G, Agudo A, Travier N, et al. Adherence to the Mediterranean diet reduces mortality in the Spanish cohort of the European Prospective Investigation into Cancer and Nutrition (EPIC-Spain). Br J Nutr. 2011;106(10):1581-91. doi:10.1017/S0007114511002078 | | X | X
135 | Bui Q. Dietary fat modification and the risk of future cardiovascular events and mortality. Am Fam Physician. 2013;87(9):609-10. | X
136 | Bumrungpert A, Chongsuwat R, Phosat C, Butacnum A. Rice bran oil containing gamma-oryzanol improves lipid profiles and antioxidant status in hyperlipidemic subjects: A randomized double-blind controlled trial. J Altern Complement Med. 2019;25(3):353-358. doi:10.1089/acm.2018.0212 | | | | Health Status
137 | Butler TJ, Davies I, Mushtaq S. Full fat cheese intake and cardiovascular health: a randomised control trial. Proceedings of the nutrition society. 2017;76(OCE4): E223. doi:10.1017/S0029665117003858 | | | | Publication Status
138 | Buyken AE, Flood V, Rochtchina E, Nestel P, Brand-Miller J, Mitchell P. Modifications in dietary fat quality are associated with changes in serum lipids of older adults independently of lipid medication. J Nutr. 2010;140(1):88-94. doi:10.3945/jn.109.110486 | | | X
139 | Byrne DW, Rolando LA, Aliyu MH, et al. Modifiable healthy lifestyle behaviors: 10-Year health outcomes from a health promotion program. Am J Prev Med. 2016;51(6):1027-1037. doi:10.1016/j.amepre.2016.09.012 | | X
140 | Caligiuri SP, Rodriguez-Leyva D, Aukema HM, et al. Dietary flaxseed reduces central aortic blood pressure without cardiac involvement but through changes in plasma oxylipins. Hypertension. 2016;68(4):1031-1038. doi:10.1161/hypertensionaha.116.07834 | | | | Health Status
141 | Calyniuk B, Grochowska-Niedworok E, Muc-Wierzgon M, Nowakowska-Zajdel E, Osowski M. The effectiveness of the low energy diet in overweight and obese adults. Rocz Panstw Zakl Hig. 2016;67(2):137-46. | | X
142 | Camargo A, Rangel-Zuniga OA, Alcala-Diaz J, et al. Dietary fat may modulate adipose tissue homeostasis through the processes of autophagy and apoptosis. Eur J Nutr. 2017;56(4):1621-1628. doi:10.1007/s00394-016-1208-y | | | X
143 | Campos Mondragón MG, Oliart Ros RM, Martínez Martinez A, Méndez Machado GF, Angulo Guerrero JO. Metabolic syndrome reversion by polyunsaturated fatty acids ingestion. Med Clin. 2013;141(12):513- 518. doi:10.1016/j.medcli.2012.10.030 | | | | Language
144 | Campos-Staffico AM, Costa APR, Carvalho LSF, et al. Omega-3 intake is associated with attenuated inflammatory response and cardiac remodeling after myocardial infarction. Nutr J. 2019;18(1):29. doi:10.1186/s12937-019-0455-1 | | | X
145 | Cao Y, Wittert G, Taylor AW, Adams R, Appleton S, Shi Z. Nutrient patterns and chronic inflammation in a cohort of community dwelling middle-aged men. Clin Nutr. 2017;36(4):1040-1047. doi:10.1016/j.clnu.2016.06.018 | | X | X
146 | Cardoso Chaves O, Franceschini Sdo C, Machado Rocha Ribeiro S, Ferreira Rocha Sant Ana L, Garcon de Faria C, Priore SE. Anthropometric and biochemical parameters in adolescents and their relationship with eating habits and household food availability. Nutr Hosp. 2013;28(4):1352-6. doi:10.3305/nh.2013.28.4.6467 | X | X
147 | Carson JA, Michalsky L, Latson B, et al. The cardiovascular health of urban African Americans: diet-related results from the Genes, Nutrition, Exercise, Wellness, and Spiritual Growth (GoodNEWS) trial. J Acad Nutr Diet. 2012;112(11):1852-8. doi:10.1016/j.jand.2012.06.357 | | X | X
148 | Carvalho-Wells AL, Jackson KG, Lockyer S, Lovegrove JA, Minihane AM. APOE genotype influences triglyceride and C-reactive protein responses to altered dietary fat intake in UK adults. Am J Clin Nutr. 2012;96(6):1447-53. doi:10.3945/ajcn.112.043240 | | | X
149 | Casas R, Sacanella E, Urpi-Sarda M, et al. The effects of the mediterranean diet on biomarkers of vascular wall inflammation and plaque vulnerability in subjects with high risk for cardiovascular disease. A randomized trial. PLoS One. 2014;9(6):e100084. doi:10.1371/journal.pone.0100084 | | X
150 | Casas R, Sacanella E, Urpi-Sarda M, et al. Long-term immunomodulatory effects of a Mediterranean diet in adults at high risk of cardiovascular disease in the PREvencion con DIeta MEDiterranea (PREDIMED) Randomized Controlled Trial. J Nutr. 2016;146(9):1684-93. doi:10.3945/jn.115.229476 | | X | | Health Status
151 | Casas-Agustench P, Serra M, Perez-Heras A, Cofan M, Pinto X, Trautwein EA, Ros E. Effects of plant sterol esters in skimmed milk and vegetable-fat-enriched milk on serum lipids and non-cholesterol sterols in hypercholesterolaemic subjects: a randomised placebo-controlled cross over study. Br J Nutr. 2012;107(12):1766-75. doi:10.1017/s0007114511005162 | | X
152 | Casazza K, Dulin-Keita A, Gower BA, Fernandez JR. Differential influence of diet and physical activity on components of metabolic syndrome in a multiethnic sample of children. J Am Diet Assoc. 2009. 109(2):236-44. doi:10.1016/j.jada.2008.10.054 | X
153 | Celada P, Delgado-Pando G, Olmedilla-Alonso B, JimenezColmenero F, Ruperto M, Sanchez-Muniz FJ. Impact of improved fat-meat products consumption on anthropometric markers and nutrient intakes of male volunteers at increased cardiovascular risk. Nutr Hosp. 2015;32(2):710-21. doi:10.3305/nh.2015.32.2.9231 | | | X
154 | Celada P, Olmedilla-Alonso B, Delgado-Pando G, et al. Coagulation, thrombogenesis, and insulin resistance markers in increased-cardiovascular-risk subjects consuming improved-fat meat products. J Am Coll Nutr. 2019;38(4):334-341. doi:10.1080/07315724.2018.1513345 | | | | Health Status
155 | Celada P, Sanchez-Muniz FJ, Delgado-Pando G, et al. Effects of improved fat meat products consumption on emergent cardiovascular disease markers of male volunteers at cardiovascular risk. J Physiol Biochem. 2016;72(4):669-678. doi:10.1007/s13105-016-0505-5 | | X | | Health Status
156 | Cervenka MC, Patton K, Eloyan A, Henry B, Kossoff EH. The impact of the modified Atkins diet on lipid profiles in adults with epilepsy. Nutr Neurosci. 2016;19(3):131-7. doi:10.1179/1476830514y.0000000162 | X | X
157 | Cha D, Park Y. Association between dietary cholesterol and their food sources and risk for hypercholesterolemia: The 2012-2016 Korea National Health and Nutrition Examination Survey. Nutrients. 2019;11(4): pii: E846. doi:10.3390/nu11040846 | X
158 | Cha E, Paul S, Braxter BJ, Umpierrez G, Faulkner MS. Dietary behaviors and glucose metabolism in young adults at risk for type 2 diabetes. Diabetes Educ. 2018;44(2):158-167. doi:10.1177/0145721718756057 | X
159 | Chahal N, McCrindle B, Manlhiot C, Wong H. A 4-week randomized clinical trial of flaxseed supplementation in children with hypercholesterolemia. Canadian journal of cardiology. 2011. 27(5 Suppl):S339. doi:10.1016/j.cjca.2011.08.006 | | | | Publication Status
160 | Champagne CM, Broyles ST, Moran LD, et al. Dietary intakes associated with successful weight loss and maintenance during the Weight Loss Maintenance trial. J Am Diet Assoc. 2011;111(12):1826-35. doi:10.1016/j.jada.2011.09.014 | | X
161 | Chang L, Vethakkan S, Nesaretnam K, Teng K. Effects of exchanging dietary saturated fatty acids or carbohydrate for monounsaturated fatty acids on inflammatory responses in abdominally obese Malaysians: a randomized controlled trial. Obesity reviews. 2014. 15:94. doi:10.1111/obr.12149 | | | | Publication Status
162 | Chang WI, Azrina A, Sabariah MN, Irmi Zarina I, Loh SP. Effects of consuming yellowstripe scad versus salmon on lipid profile, fasting glucose, body weight status and blood pressure among healthy overweight Malaysian adults. Malays J Nutr. 2017;23(3):434-452. | | X
163 | Chee C, Mansell P, Stephens F, et al. Differential effects of carbohydrate vs fat overfeeding on liver fat content and lipid metabolism in healthy overweight males. Diabetologia. 2015. 58(Suppl. 1):S336. doi:10.1007/s00125-015-3687-4 | | | | Publication Status
164 | Cheenam B, Leena P, Vikas K. Effects of sunflower seeds on cholesterol and low-density lipoprotein levels in patients with dyslipidemia. Asian J Pharm Clin Res. 2019;12(3):556-559. doi:10.22159/ajpcr.2019.v12i3.31032 | | | | Health Status, Country
165 | Chen BK, Seligman B, Farquhar JW, Goldhaber-Fiebert JD. Multi-Country analysis of palm oil consumption and cardiovascular disease mortality for countries at different stages of economic development: 1980-1997. Global Health. 2011;745. doi:10.1186/1744-8603-7-45 | X
166 | Chen M, Li Y, Sun Q, et al. Dairy fat and risk of cardiovascular disease in 3 cohorts of US adults. Am J Clin Nutr. 2016;104(5):1209-1217. doi:10.3945/ajcn.116.134460 | X
167 | Chen ST, Maruthur NM, Appel LJ. The effect of dietary patterns on estimated coronary heart disease risk: results from the Dietary Approaches to Stop Hypertension (DASH) trial. Circ Cardiovasc Qual Outcomes. 2010;3(5):484-9. doi:10.1161/circoutcomes.109.930685 | | X
168 | Chen Y, Estampador AC, Keller M, et al. The combined effects of FADS gene variation and dietary fats in obesity-related traits in a population from the far north of Sweden: the GLACIER Study. Int J Obes (Lond). 2019;43(4):808-820. doi:10.1038/s41366-018-0112-3 | X | | X
169 | Chen Y, Feng R, Yang X, et al. Yogurt improves insulin resistance and liver fat in obese women with nonalcoholic fatty liver disease and metabolic syndrome: A randomized controlled trial. Am J Clin Nutr. 2019;109(6):1611-1619. doi:10.1093/ajcn/nqy358 | | X
170 | Chiang YL, Haddad E, Rajaram S, Shavlik D, Sabate J. The effect of dietary walnuts compared to fatty fish on eicosanoids, cytokines, soluble endothelial adhesion molecules and lymphocyte subsets: a randomized, controlled crossover trial. Prostaglandins Leukot Essent Fatty Acids. 2012;87(4-5):111-7. doi:10.1016/j.plefa.2012.07.007 | | X | X
171 | Chiu S, Bergeron N, Williams PT, Bray GA, Sutherland B, Krauss RM. Comparison of the DASH (Dietary Approaches to Stop Hypertension) diet and a higher-fat DASH diet on blood pressure and lipids and lipoproteins: a randomized controlled trial. Am J Clin Nutr. 2016;103(2):341-7. doi:10.3945/ajcn.115.123281 | | X
172 | Chiu S, Krauss RM. The effects of high saturated fat intake on LDL and HDL subclasses in individuals with atherogenic dyslipidemia. Circulation. 2012;125(Suppl 10): AP348. | | | | Publication Status
173 | Chiu S, Williams PT, Krauss RM. Effects of a very high saturated fat diet on LDL particles in adults with atherogenic dyslipidemia: A randomized controlled trial. PLoS One. 2017;12(2):e0170664. doi:10.1371/journal.pone.0170664 | | | X | Study Duration
174 | Chiuve SE, Sandhu RK, Moorthy MV, Glynn RJ, Albert CM. Dietary fat intake is differentially associated with risk of paroxysmal compared with sustained atrial fibrillation in women. J Nutr. 2015;145(9):2092-101. doi:10.3945/jn.115.212860 | | | X | Population at Outcome
175 | Chiva-Blanch G, Laake K, Myhre P, et al. High adherence to the Nordic diet is associated with lower levels of total and platelet-derived circulating microvesicles in a Norwegian population. Nutrients. 2019;11(5): pii: E1114. doi:10.3390/nu11051114 | X | X
176 | Chmurzynska A, Muzsik A, Krzyzanowska-Jankowska P, Walkowiak J, Bajerska J. The effect of habitual fat intake, IL6 polymorphism, and different diet strategies on inflammation in postmenopausal women with central obesity. Nutrients. 2019;11(7): pii: E1557. doi:10.3390/nu11071557 | | | X
177 | Cho Y, Cudhea F, Park JH, Mozaffarian D, Singh G, Shin MJ. Burdens of cardiometabolic diseases attributable to dietary and metabolic risks in Korean adults 2012–2013. Yonsei Med J. 2017;58(3):540-551. doi:10.3349/ymj.2017.58.3.540 | X
178 | Christofaro DG, Fernandes RA, Oliveira AR, Freitas Junior IF, Barros MV, Ritti-Dias RM. The association between cardiovascular risk factors and high blood pressure in adolescents: a school-based study. Am J Hum Biol. 2014;26(4):518-22. doi:10.1002/ajhb.22555 | | X
179 | Clark ML, Butler LM, Koh WP, Wang R, Yuan JM. Dietary fiber intake modifies the association between secondhand smoke exposure and coronary heart disease mortality among Chinese non-smokers in Singapore. Nutrition. 2013;29(11-12):1304-9. doi:10.1016/j.nut.2013.04.003 | | X
180 | Clifton P. Metabolic syndrome-role of dietary fat type and quantity. Nutrients. 2019;11(7): pii: E1438. doi:10.3390/nu11071438 | X
181 | Coates AM, Sioutis S, Buckley JD, Howe PRC. Regular consumption of n-3 fatty acid-enriched pork modifies cardiovascular risk factors. Br J Nutr. 2009. 101(4):592-597. doi:10.1017/S0007114508025063 | | | | Age of participants at intervention or exposure
182 | Colussi G, Catena C, Dialti V, Pezzutto F, Mos L, Sechi LA. Fish meal supplementation and ambulatory blood pressure in patients with hypertension: relevance of baseline membrane fatty acid composition. Am J Hypertens. 2014;27(3):471-81. doi:10.1093/ajh/hpt231 | | X | | Health Status
183 | Conte FA, Franz LB, Berlezi EM, Oliveira OB. Nutritional education and olive oil improve dislipidemia of climate women. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2017;11(8):3100-3107. doi:10.5205/reuol.11064-98681-4-ED.1108201715 | | | | Health Status
184 | Conway MC, Mulhern MS, McSorley EM, et al. Dietary determinants of polyunsaturated fatty acid (PUFA) status in a high fish-eating cohort during pregnancy. Nutrients. 2018;10(7): pii: E927. doi:10.3390/nu10070927 | | | X
185 | Conway V, Couture P, Richard C, Gauthier SF, Pouliot Y, Lamarche B. Impact of buttermilk consumption on plasma lipids and surrogate markers of cholesterol homeostasis in men and women. Nutr Metab Cardiovasc Dis. 2013;23(12):1255-62. doi:10.1016/j.numecd.2013.03.003 | | X
186 | Corella D, Sorli JV, Estruch R, et al. MicroRNA-410 regulated lipoprotein lipase variant rs13702 is associated with stroke incidence and modulated by diet in the randomized controlled PREDIMED trial. Am J Clin Nutr. 2014;100(2):719-31. doi:10.3945/ajcn.113.076992 | | X
187 | Corina A, Rangel-Zuniga OA, Jimenez-Lucena R, et al. Low intake of vitamin E accelerates cellular aging in patients with established cardiovascular disease: The CORDIOPREV Study. J Gerontol A Biol Sci Med Sci. 2019;74(6):770-777. doi:10.1093/gerona/gly195 | | | X | Health Status
188 | Crichton GE, Alkerwi A. Dairy food intake is positively associated with cardiovascular health: findings from Observation of Cardiovascular Risk Factors in Luxembourg study. Nutr Res. 2014;34(12):1036-44. doi:10.1016/j.nutres.2014.04.002 | X | | X
189 | Crowe-White KM, Cardel MI, Burkhalter HH, Huo T, Fernandez JR. Higher n-6:n-3 fatty acid intake is associated with decreased cardiometabolic risk factors in a racially diverse sample of children. Curr Dev Nutr. 2018;2(5):nzy014. doi:10.1093/cdn/nzy014 | X
190 | Cruz ML, Wong WW, Mimouni F, et al. Effects of infant nutrition on cholesterol synthesis rates. Pediatr Res. 1994. 35(2):135-40. doi:10.1203/00006450-199402000-00001 | | X
191 | Cueto-Galan R, Baron FJ, Valdivielso P, et al. Changes in fatty liver index after consuming a Mediterranean diet: 6-year follow-up of the PREDIMED-Malaga trial. Med Clin (Barc). 2017;148(10):435-443. doi:10.1016/j.medcli.2016.11.032 | | | X
192 | Cundiff DK, Lanou AJ, Nigg CR. Relation of omega-3 Fatty Acid intake to other dietary factors known to reduce coronary heart disease risk. Am J Cardiol. 2007. 99(9):1230-3. doi:10.1016/j.amjcard.2006.12.032 | | | X
193 | Curb JD, Wergowske G, Dobbs JC, Abbott RD, Huang B. Serum lipid effects of a high-monounsaturated fat diet based on macadamia nuts. Arch Intern Med. 2000. 160(8):1154-8. doi:10.1001/archinte.160.8.1154 | | | | Age of participants at intervention or exposure
194 | da Luz P, Nishiyama M, Chagas ACP. Drugs and lifestyle for the treatment and prevention of coronary artery disease - comparative analysis of the scientific basis. Braz J Med Biol Res. 2011;44(10):973-991. doi:10.1590/S0100-879X2011007500111 | X
195 | Da Silva MS, Julien P, Couture P, Lemieux S, Vohl MC, Rudkowska I. Associations between dairy intake and metabolic risk parameters in a healthy French-Canadian population. Appl Physiol Nutr Metab. 2014;39(12):1323-31. doi:10.1139/apnm-2014-0154 | X | X
196 | Daci A, Ozen G, Uyar I, et al. Omega-3 polyunsaturated fatty acids reduce vascular tone and inflammation in human saphenous vein. Prostaglandins Other Lipid Mediat. 2017;133:29-34. doi:10.1016/j.prostaglandins.2017.08.007 | | | | Health Status, Non-human
197 | Dai J, Jiang Z, Zhang B. Exercise and nutrition therapy for simple obesity in children. Chinese journal of clinical rehabilitation. 2006. 10(32):20- 22. | | | | Language
198 | Dalbeni A, Treggiari D, Tagetti A, et al. Positive effects of tomato paste on vascular function after a fat meal in male healthy subjects. Nutrients. 2018;10(9): pii: E1310. doi:10.3390/nu10091310 | | X
199 | Dalmeijer GW, Struijk EA, van der Schouw YT, et al. Dairy intake and coronary heart disease or stroke--a population-based cohort study. Int J Cardiol. 2013;167(3):925-9. doi:10.1016/j.ijcard.2012.03.094 | | X
200 | Damasceno NR, Perez-Heras A, Serra M, et al. Crossover study of diets enriched with virgin olive oilwalnuts or almonds. Effects on lipids and other cardiovascular risk markers. Nutr Metab Cardiovasc Dis. 2011;21(Suppl 1):S14-20. doi:10.1016/j.numecd.2010.12.006 | | | | Health Status
201 | Damasceno NR, Sala-Vila A, Cofan M, et al. Mediterranean diet supplemented with nuts reduces waist circumference and shifts lipoprotein subfractions to a less atherogenic pattern in subjects at high cardiovascular risk. Atherosclerosis. 2013;230(2):347-53. doi:10.1016/j.atherosclerosis.2013.08.014 | | X
202 | Damsgaard CT, Lauritzen L, Hauger H, et al. Effects of oily fish intake on cardiovascular risk markerscognitive functionand behavior in school-aged children: study protocol for a randomized controlled trial. Trials. 2016;17(1):510. doi:10.1186/s13063-016-1647-z | X | X | X
203 | Damsgaard CT, Ritz C, Dalskov SM, et al. Associations between school meal-induced dietary changes and metabolic syndrome markers in 8-11-year-old Danish children. Eur J Nutr. 2016;55(5):1973-84. doi:10.1007/s00394-015-1013-z | | X
204 | Daniels SR. Diet and primordial prevention of cardiovascular disease in children and adolescents. Circulation. 2007. 116(9):973- 974. doi:10.1161/circulationaha.107.723817 | X
205 | Daryani A, Becker W, Vessby B, Andersson A. Dietary fat intakefat sources and fatty acid composition in serum among immigrant women from Iran and Turkey compared with women of Swedish ethnicity. Scandinavian Journal of Nutrition. 2005. 49(3):106-115. | | X
206 | Davinelli S, Corbi G, Zarrelli A, et al. Short-term supplementation with flavanol-rich cocoa improves lipid profileantioxidant status and positively influences the AA/EPA ratio in healthy subjects. J Nutr Biochem. 2018;6133-39. doi:10.1016/j.jnutbio.2018.07.011 | | X
207 | Davis CR, Bryan J, Hodgson JM, Woodman R, Murphy KJ. A Mediterranean diet reduces F2-isoprostanes and triglycerides among older Australian men and women after 6 months. J Nutr. 2017;147(7):1348-1355. doi:10.3945/jn.117.248419 | | X
208 | Davis CR, Hodgson JM, Woodman R, Bryan J, Wilson C, Murphy KJ. A Mediterranean diet lowers blood pressure and improves endothelial function: results from the MedLey randomized intervention trial. Am J Clin Nutr. 2017;105(6):1305-1313. doi:10.3945/ajcn.116.146803 | | X
209 | Davis KE, Prasad C, Imrhan V. Consumption of a diet rich in cottonseed oil (CSO) lowers total and LDL cholesterol in normo-cholesterolemic subjects. Nutrients. 2012;4(7):602-10. doi:10.3390/nu4070602 | X
210 | Davison KM, Kaplan BJ. Food intake and blood cholesterol levels of community-based adults with mood disorders. BMC Psychiatry. 2012;1210. doi:10.1186/1471-244x-12-10 | X | | | Health Status
211 | Davy BM, Harrell K, Stewart J, King DS. Body weight status, dietary habits and physical activity levels of middle school-aged children in rural Mississippi. South Med J. 2004. 97(6):571-7. doi:10.1097/00007611-200406000-00012 | | | X
212 | Dawczynski C, Massey KA, Ness C, et al. Randomized placebo-controlled intervention with n-3 LC-PUFA-supplemented yoghurt: effects on circulating eicosanoids and cardiovascular risk factors. Clin Nutr. 2013;32(5):686-96. doi:10.1016/j.clnu.2012.12.010 | | X | | Health Status
213 | de Batlle J, Sauleda J, Balcells E, et al. Association between Omega3 and Omega6 fatty acid intakes and serum inflammatory markers in COPD. J Nutr Biochem. 2012;23(7):817-21. doi:10.1016/j.jnutbio.2011.04.005 | X | | X
214 | de la Torre NG, Assaf-Balut C, Jimenez Varas I, et al. Effectiveness of following Mediterranean diet recommendations in the real world in the incidence of gestational diabetes mellitus (gdm) and adverse maternal-foetal outcomes: a prospective, universal, interventional study with a single group. The St Carlos Study. Nutrients. 2019;11(6): pii: E1210. doi:10.3390/nu11061210 | | X | X
215 | de Luis D, Izaola O, Primo D, Aller R. Role of rs670 variant of APOA1 gene on metabolic response after a high fat vs. a low fat hypocaloric diets in obese human subjects. J Diabetes Complications. 2019;33(3):249-254. doi:10.1016/j.jdiacomp.2018.10.015 | | X
216 | de Luis DA, Aller R, Izaola O, Bachiller R, Pacheco D. Cardiovascular risk factors and adipocytokines levels after two hypocaloric diets with different fat distribution in obese subjects and rs6923761 gene variant of glucagon-like peptide 1 receptor. J Endocrinol Invest. 2014;37(9):853-9. doi:10.1007/s40618-014-0116-3 | | X
217 | de Luis DA, Aller R, Izaola O, Gonzalez Sagrado M, Conde R. Role of G308 promoter variant of tumor necrosis factor alpha gene on weight loss and metabolic parameters after a high monounsaturated versus a high polyunsaturated fat hypocaloric diets. Med Clin (Barc). 2013;141(5):189-93. doi:10.1016/j.medcli.2012.12.021 | | X
218 | De Luis DA, Aller R, Izaola O, Pacheco D. Role of rs9939609 FTO gene variant in weight loss, insulin resistance and metabolic parameters after a high monounsaturated vs a high polyunsaturated fat hypocaloric diets. Nutr Hosp. 2015;32(1):175-81. doi:10.3305/nh.2015.32.1.9169 | | X
219 | de Luis DA, Izaola O, Primo D, Aller R. Dietary-fat effect of the rs10830963 polymorphism in MTNR1B on insulin resistance in response to 3 months weight-loss diets. Endocrinol Diabetes Nutr. 2019;doi:10.1016/j.endinu.2019.02.007 | | X
220 | de Luis DA, Izaola O, Primo D, Aller R. Impact of 2 different hypocaloric diets on serum omentin levels in obese subjects. Ann Nutr Metab. 2018;73(2):138-144. doi:10.1159/000489130 | | X
221 | de Luis DA, Izaola O, Primo D, Aller R. Single nucleotide polymorphisms at the ADIPOQ gene locus rs1501299 interact with different type of dietary fatty acids in two hypocaloric diets. Eur Rev Med Pharmacol Sci. 2019;23(7):2960-2970. doi:10.26355/eurrev_201904_17577 | X | X
222 | de Luis DA, Romero E, Izaola O, Primo D, Aller R. Cardiovascular risk factors and insulin resistance after two hypocaloric diets with different fat distribution in obese subjects: effect of the rs10767664 gene variant in brain-derived neurotrophic factor. J Nutrigenet Nutrigenomics. 2017;10(5-6):163-171. doi:10.1159/000485248 | | X
223 | De Natale C, Minerva V, Patti L, et al. Effects of baked products enriched with n-3 fatty acids, folates, beta-glucans, and tocopherol in patients with mild mixed hyperlipidemia. J Am Coll Nutr. 2012;31(5):311-9. doi:10.1080/07315724.2012.10720427 | | X
224 | de Oliveira Otto MC, Nettleton JA, Lemaitre RN, et al. Biomarkers of dairy fatty acids and risk of cardiovascular disease in the Multi-ethnic Study of Atherosclerosis. J Am Heart Assoc. 2013;2(4):e000092. doi:10.1161/jaha.113.000092 | | X
225 | de Roos N, Schouten E, Katan M. Consumption of a solid fat rich in lauric acid results in a more favorable serum lipid profile in healthy men and women than consumption of a solid fat rich in trans-fatty acids. J Nutr. 2001. 131(2):242-5. doi:10.1093/jn/131.2.242 | | X | | Age of participants at intervention or exposure
226 | Dearborn JL, Qiao Y, Guallar E, et al. Polyunsaturated fats, carbohydrates and carotid disease: The Atherosclerosis Risk in Communities (ARIC) Carotid MRI study. Atherosclerosis. 2016;251361-366. doi:10.1016/j.atherosclerosis.2016.05.024 | | | X | Health Status
227 | DeHaven MJ, Ramos-Roman MA, Gimpel N, et al. The GoodNEWS (Genes, Nutrition, Exercise, Wellness, and Spiritual Growth) Trial: a community-based participatory research (CBPR) trial with African-American church congregations for reducing cardiovascular disease risk factors--recruitmentmeasurementand randomization. Contemp Clin Trials. 2011;32(5):630-40. doi:10.1016/j.cct.2011.05.017 | X | X
228 | Dehghan M, Mente A, Rangarajan S, et al. Association of dairy intake with cardiovascular disease and mortality in 21 countries from five continents (PURE): a prospective cohort study. Lancet. 2018;392(10161):2288-2297. doi:10.1016/s0140-6736(18)31812-9 | | | | Country
229 | Dehghan M, Mente A, Zhang X, et al. Associations of fats and carbohydrate intake with cardiovascular disease and mortality in 18 countries from five continents (PURE): a prospective cohort study. Lancet. 2017;390(10107):2050-2062. doi:10.1016/s0140-6736(17)32252-3 | | | | Country
230 | Del Bo C, Simonetti P, Gardana C, Riso P, Lucchini G, Ciappellano S. Horse meat consumption affects iron status, lipid profile and fatty acid composition of red blood cells in healthy volunteers. Int J Food Sci Nutr. 2013;64(2):147-54. doi:10.3109/09637486.2012.728198 | | X
231 | Del Brutto OH, Costa AF, Cano JA, et al. Low prevalence of atrial fibrillation in amerindians: a population-based study in frequent fish consumers livinin rural coastal ecuador (The Atahualpa project). Aging Clin Exp Res. 2018;30(5):539-542. doi:10.1007/s40520-017-0810-z | | X | X
232 | Del Brutto OH, Mera RM, Ha JE, et al. Oily fish consumption is inversely correlated with cerebral microbleeds in community-dwelling older adults: results from the Atahualpa Project. Aging Clin Exp Res. 2016. 28(4):737-743. doi:10.1007/s40520-015-0473-6 | | X | X
233 | dela Paz C, Jimeno C, Sy R, Punzalan FE, dela Pena P. The effect of virgin coconut oil on lipid profile and fasting blood sugar: A phase I clinical trial. Phillippine Journal of Internal Medicine. 2010;48(2):1-6. | | X | | Country
234 | Delgado-Lista J, Perez-Martinez P, Garcia-Rios A, et al. CORonary Diet Intervention with Olive oil and cardiovascular PREVention study (the CORDIOPREV study): Rationalemethodsand baseline characteristics: A clinical trial comparing the efficacy of a Mediterranean diet rich in olive oil versus a low-fat diet on cardiovascular disease in coronary patients. Am Heart J. 2016;177:42-50. doi:10.1016/j.ahj.2016.04.011 | X | | X
235 | Delgado-Pando G, Celada P, Sanchez-Muniz FJ, Jimenez-Colmenero F, Olmedilla-Alonso B. Effects of improved fat content of frankfurters and pates on lipid and lipoprotein profile of volunteers at increased cardiovascular risk: a placebo-controlled study. Eur J Nutr. 2014;53(1):83-93. doi:10.1007/s00394-013-0502-1 | | | | Health Status
236 | Demmers TA, Jones PJ, Wang Y, Krug S, Creutzinger V, Heubi JE. Effects of early cholesterol intake on cholesterol biosynthesis and plasma lipids among infants until 18 months of age. Pediatrics. 2005. 115(6):1594-601. doi:10.1542/peds.2004-0997 | | X
237 | Derkach A, Sampson J, Joseph J, Playdon MC, Stolzenberg-Solomon RZ. Effects of dietary sodium on metabolites: the Dietary Approaches to Stop Hypertension (DASH)-Sodium Feeding Study. Am J Clin Nutr. 2017;106(4):1131-1141. doi:10.3945/ajcn.116.150136 | | X | X
238 | Detopoulou P, Fragopoulou E, Alepoudea E, Nomikos T, Kalogeropoulos N, Antonopoulou S. Associations between erythrocyte fatty acids and Mediterranean diet in Greek volunteers. Hellenic Journal of Atherosclerosis. 2018;9(1):17-31. | X
239 | Devadawson C, Jayasinghe C, Ramiah S, Kanagasingam A. Assessment of lipid profile and atherogenic indices for cardiovascular disease risk based on different fish consumption habits. Asian J Pharm Clin Res. 2016;9(4):156-160. | X | X
240 | Devarajan S, Singh R, Chatterjee B, Zhang B, Ali A. A blend of sesame oil and rice bran oil lowers blood pressure and improves the lipid profile in mild-to-moderate hypertensive patients. J Clin Lipidol. 2016;10(2):339-49. doi:10.1016/j.jacl.2015.12.011 | | | | Health Status, Country
241 | Dewailly E, Blanchet C, Gingras S, Lemieux S, Holub BJ. Cardiovascular disease risk factors and n-3 fatty acid status in the adult population of James Bay Cree. Am J Clin Nutr. 2002;76(1):85-92. doi:10.1093/ajcn/76.1.85 | | X
242 | Dhillon J, Li Z, Ortiz RM. Almond Snacking for 8 wk Increases Alpha-Diversity of the Gastrointestinal Microbiome and Decreases Bacteroides fragilis Abundance Compared with an Isocaloric Snack in College Freshmen. Curr Dev Nutr. 2019;3(8):nzz079. doi:10.1093/cdn/nzz079 | | | X
243 | Di Stefano R, Felice F, Belardinelli E, et al. Extra virgin olive oil and apples enriched-dark chocolate consumption and endothelial function: a randomized crossover trial in patients with cardiovascular risk factors. Eur Heart J. 2017;381119- 1120. doi:10.1093/eurheartj/ehx502.P5319 | | | | Publication Status
244 | Diaf M, Khaled MB, Sellam F. Correlation between dietary fat intake and atherogenic indices in normaloverweight and obese adults with or without type 2 diabetes. Rom J Diabetes Nutr and Metab Dis. 2015;22(4):347-360. doi:10.1515/rjdnmd-2015-0041 | | X
245 | Dias CB, Amigo N, Wood LG, Mallol R, Correig X, Garg ML. Improvement of the omega 3 index of healthy subjects does not alter the effects of dietary saturated fats or n-6PUFA on LDL profiles. Metabolism. 2017;6811-19. doi:10.1016/j.metabol.2016.11.014 | | | | Study Duration
246 | Diaz-Lopez A, Bullo M, Martinez-Gonzalez MA, et al. Dairy product consumption and risk of type 2 diabetes in an elderly Spanish Mediterranean population at high cardiovascular risk. Eur J Nutr. 2016;55(1):349-60. doi:10.1007/s00394-015-0855-8 | | | X
247 | Diaz-Lopez A, Bullo M, Martinez-Gonzalez MA, et al. Effects of Mediterranean diets on kidney function: a report from the PREDIMED trial. Am J Kidney Dis. 2012;60(3):380-9. doi:10.1053/j.ajkd.2012.02.334 | | | X
248 | Diekmann C, Huber H, Preuss M, et al. Moderate postmeal walking has no beneficial effects over resting on postprandial lipemia, glycemia, insulinemia, and selected oxidative and inflammatory parameters in older adults with a cardiovascular disease risk phenotype: A randomized crossover trial. J Nutr. 2019;149(11):1930-1941. doi:10.1093/jn/nxz148 | | X | X
249 | Diez-Espino J, Basterra-Gortari FJ, Salas-Salvado J, et al. Egg consumption and cardiovascular disease according to diabetic status: The PREDIMED study. Clin Nutr. 2017;36(4):1015-1021. doi:10.1016/j.clnu.2016.06.009 | | X
250 | DiMarco DM, Norris GH, Millar CL, Blesso CN, Fernandez ML. Intake of up to 3 eggs per day is associated with changes in HDL function and increased plasma antioxidants in healthy, young adults. J Nutr. 2017;147(3):323-329. doi:10.3945/jn.116.241877 | | X
251 | Dimitriou M, Rallidis LS, Theodoraki EV, Kalafati IP, Kolovou G, Dedoussis GV. Exclusive olive oil consumption has a protective effect on coronary artery disease; overview of the THISEAS study. Public Health Nutr. 2016;19(6):1081-7. doi:10.1017/s1368980015002244 | X
252 | Din JN, Aftab SM, Jubb AW, et al. Effect of moderate walnut consumption on lipid profilearterial stiffness and platelet activation in humans. Eur J Clin Nutr. 2011;65(2):234-9. doi:10.1038/ejcn.2010.233 | | X | X
253 | DiNicolantonio JJ, O’Keefe JH. Omega-6 vegetable oils as a driver of coronary heart disease: the oxidized linoleic acid hypothesis. Open Heart. 2018;5(2):e000898. doi:10.1136/openhrt-2018-000898 | X
254 | Dittrich M, Jahreis G, Bothor K, et al. Benefits of foods supplemented with vegetable oils rich in alpha-linolenic, stearidonic or docosahexaenoic acid in hypertriglyceridemic subjects: a double-blind, randomized, controlled trail. Eur J Nutr. 2015;54(6):881-93. doi:10.1007/s00394-014-0764-2 | | X | | Health Status
255 | Dixon LB, Shannon BM, Tershakovec AM, Bennett MJ, Coates PM, Cortner JA. Effects of family history of heart disease, apolipoprotein E phenotype, and lipoprotein(a) on the response of children’s plasma lipids to change in dietary lipids. Am J Clin Nutr. 1997. 66(5):1207-17. doi:10.1093/ajcn/66.5.1207 | | X | | Health Status
256 | Djousse L, Petrone AB, Gaziano JM. Consumption of fried foods and risk of heart failure in the physicians’ health study. J Am Heart Assoc. 2015;4(4): pii: e001740. doi:10.1161/jaha.114.001740 | | X
257 | Dodevska MS, Sobajic SS, Djordjevic PB, Dimitrijevic-Sreckovic VS, Spasojevic-Kalimanovska VV, Djordjevic BI. Effects of total fibre or resistant starch-rich diets within lifestyle intervention in obese prediabetic adults. Eur J Nutr. 2016;55(1):127-37. doi:10.1007/s00394-015-0831-3 | | X
258 | Dolley G, Boisclair ME, Lamarche B, et al. Interactions between dietary fat intake and FASN genetic variation influence LDL peak particle diameter. J Nutrigenet Nutrigenomics. 2011;4(3):137-45. doi:10.1159/000327778 | X | X
259 | Domenech M, Roman P, Lapetra J, et al. Mediterranean diet reduces 24-hour ambulatory blood pressureblood glucose, and lipids: one-year randomized, clinical trial. Hypertension. 2014;64(1):69-76. doi:10.1161/hypertensionaha.113.03353 | | X
260 | Dominguez-Reyes T, Astudillo-Lopez CC, Salgado-Goytia L, et al. Interaction of dietary fat intake with APOA2, APOA5 and LEPR polymorphisms and its relationship with obesity and dyslipidemia in young subjects. Lipids Health Dis. 2015;14:106. doi:10.1186/s12944-015-0112-4 | X
261 | Doo M, Won S, Kim Y. Association between the APOB rs1469513 polymorphism and obesity is modified by dietary fat intake in Koreans. Nutrition. 2015;31(5):653-8. doi:10.1016/j.nut.2014.10.007 | X | X
262 | Doostvandi T, Bahadoran Z, Mozaffari-Khosravi H, Tahmasebinejad Z, Mirmiran P, Azizi F. The association of dietary patterns and the incidence of insulin resistance after a 3-year follow-up: Tehran Lipid and Glucose Study. Asia Pac J Clin Nutr. 2017;26(3):531-538. doi:10.6133/apjcn.032016.12 | | X | X
263 | Dore D, de Hoog J, Giles G, Ding C, Cicuttini F, Jones G. A longitudinal study of the association between dietary factorsserum lipidsand bone marrow lesions of the knee. Arthritis Res Ther. 2012;14(1):R13. doi:10.1186/ar3689 | | | X
264 | Dorgan JF, Hunsberger SA, McMahon RP, et al. Diet and sex hormones in girls: findings from a randomized controlled clinical trial. J Natl Cancer Inst. 2003. 95(2):132-141. doi:10.1093/jnci/95.2.132 | | | X
265 | Dorgan JF. Adolescent diet and metabolic syndrome components in young women: results of the dietary intervention study in children (DISC) follow-up study. Am J Epidemiol. 2011;173:S278. doi:10.1093/aje/kwr181 | | | | Publication Status
266 | Dow CA, Stauffer BL, Greiner JJ, DeSouza CA. Influence of habitual high dietary fat intake on endothelium-dependent vasodilation. Appl Physiol Nutr Metab. 2015;40(7):711-5. doi:10.1139/apnm-2015-0006 | X | X
267 | Draper CF, Vassallo I, Di Cara A, et al. A 48-Hour vegan diet challenge in healthy women and men induces a branch-chain amino acid related, health associated, metabolic signature. Mol Nutr Food Res. 2018;62(3). doi:10.1002/mnfr.201700703 | | X
268 | Drehmer M, Pereira MA, Schmidt MI, et al. Total and full-fat, but not low-fat, dairy product intakes are inversely associated with metabolic syndrome in adults. J Nutr. 2016;146(1):81-9. doi:10.3945/jn.115.220699 | X | X
269 | Dreon DM, Fernstrom HA, Williams PT, Krauss RM. Reduced LDL particle size in children consuming a very-low-fat diet is related to parental LDL-subclass patterns. Am J Clin Nutr. 2000. 71(6):1611-6. doi:10.1093/ajcn/71.6.1611 | X
270 | Drouin-Chartier JP, Tremblay AJ, Lepine MC, Lemelin V, Lamarche B, Couture P. Substitution of dietary saturated fatty acids with omega-6 polyunsaturated fatty acids decreases ldl apob-100 production rate in men with dyslipidemia associated with insulin-resistance. Circulation. 2016;134(Suppl 1):A14941. | | | | Publication Status
271 | Due A, Larsen TM, Mu H, Hermansen K, Stender S, Astrup A. Comparison of 3 ad libitum diets for weight-loss maintenance, risk of cardiovascular disease and diabetes: a 6-mo randomized, controlled trial. Am J Clin Nutr. 2008. 88(5):1232-41. doi:10.3945/ajcn.2007.25695 | | | | Age of participants at intervention or exposure
272 | Dugan CE, Aguilar D, Barona J, Luz Fernandez M. Low-fat dairy (LFD) favorably affects lipoprotein metabolism and C reactive protein (CRP) in subjects with metabolic syndrome. FASEB journal. 2012;26(Suppl 1). | | | | Publication Status
273 | Dugan CE, Barona J, Fernandez ML. Low-fat dairy differentially improves metabolic syndrome parameters in male and female adults. FASEB journal. 2013;27. doi:10.1089/met.2013.0109 | | | | Publication Status
274 | Dumont J, Goumidi L, Grenier-Boley B, et al. Dietary linoleic acid interacts with FADS1 genetic variability to modulate HDL-cholesterol and obesity-related traits. Clin Nutr. 2018;37(5):1683-1689. doi:10.1016/j.clnu.2017.07.012 | X
275 | Dyson PA, Beatty S, Matthews DR. An assessment of low-carbohydrate or low-fat diets for weight loss at 2 year’s follow-up. Diabet Med. 2010;27(3):363- 364. doi:10.1111/j.1464-5491.2010.02926.x | | X
276 | Ebell MH. Omega-3 fatty acids do not prevent cancer or cardiovascular disease events. Am Fam Physician. 2019;100(6):374-375. | X
277 | Ebrahimof S, Hosseini-Esfahani F, Mirmiran P, Fallah-Kezabi M, Azizi F. Food Patterns and Framingham Risk Score in Iranian Adults: Tehran Lipid and Glucose Study: 2005-2011. Metab Syndr Relat Disord. 2018;16(1):64-71. doi:10.1089/met.2017.0125 | | X | X
278 | Ehsani B, Moslehi N, Mirmiran P, Ramezani Tehrani F, Tahmasebinejad Z, Azizi F. A visceral adiposity index-related dietary pattern and the cardiometabolic profiles in women with polycystic ovary syndrome. Clin Nutr. 2016;35(5):1181-7. doi:10.1016/j.clnu.2015.10.007 | X | X
279 | Eloranta AM, Lindi V, Schwab U, et al. Dietary factors associated with metabolic risk score in Finnish children aged 6-8 years: the PANIC study. Eur J Nutr. 2014;53(6):1431-9. doi:10.1007/s00394-013-0646-z | X | X
280 | Engel S, Elhauge M, Tholstrup T. Effect of whole milk compared with skimmed milk on fasting blood lipids in healthy adults: a 3-week randomized crossover study. Eur J Clin Nutr. 2018;72(2):249-254. doi:10.1038/s41430-017-0042-5 | | X | | Study Duration
281 | Engel S, Tholstrup T, Bruun JM, Astrup A, Richelsen B, Raben A. Effect of high milk and sugar-sweetened and non-caloric soft drink intake on insulin sensitivity after 6 months in overweight and obese adults: a randomized controlled trial. Eur J Clin Nutr. 2018;72(3):358-366. doi:10.1038/s41430-017-0006-9 | | X
282 | Engeset D, Braaten T, Teucher B, et al. Fish consumption and mortality in the European Prospective Investigation into Cancer and Nutrition cohort. Eur J Epidemiol. 2015;30(1):57-70. doi:10.1007/s10654-014-9966-4 | | X
283 | Entezari MH, Salehi R, Kazemi M, Janghorbani M, Kafeshani M. Comparison of the effect of the Dietary Approaches to Stop Hypertension diet with usual dietary advice on expression of peroxisome proliferators-activated receptor gamma gene in women: A randomized controlled clinical trial. ARYA Atheroscler. 2018;14(1):24-31. doi:10.22122/arya.v14i1.1565 | | | X
284 | Ericson U, Brunkwall L, Alves Dias J, et al. Food patterns in relation to weight change and incidence of type 2 diabetes, coronary events and stroke in the Malmö Diet and Cancer cohort. European Journal of Nutrition. 2019;58(5):1801-1814. doi:10.1007/s00394-018-1727-9 | | X
285 | Eshriqui I, Franco-Sena AB, Farias DR, et al. Prepregnancy dietary patterns are associated with blood lipid level changes during pregnancy: a prospective cohort study in Rio de JaneiroBrazil. J Acad Nutr Diet. 2017;117(7):1066-1079.e1. doi:10.1016/j.jand.2016.12.007 | | X
286 | Essouiri J, Abourazzak FE, Lazrak F, et al. Efficacy of argane oil on metabolic syndrome in a Moroccan knee osteoarthritis population. Curr Rheumatol Rev. 2018;14(1):84-88. doi:10.2174/1573397112666161205103009 | | X | | Country
287 | Estruch R, Casas R, Sacanella E, et al. Mediterranean diet and inflammatory biomarkers. Annals of nutrition and metabolism. 2015. 67(Suppl 1):41- 42. doi:10.1159/000440895 | | | | Publication Status
288 | Estruch R, Martinez-Gonzalez MA, Corella D, et al. Effect of a high-fat Mediterranean diet on bodyweight and waist circumference: a prespecified secondary outcomes analysis of the PREDIMED randomised controlled trial. Lancet Diabetes Endocrinol. 2019;7(5):e6-e17. doi:10.1016/s2213-8587(19)30074-9 | | | X
289 | Estruch R, Martínez-González MA. Mediterranean diets reduced cardiovascular events more than a low-fat diet in high-risk persons. Annals of Internal Medicine. 2013;158(12):JC3. doi:10.7326/0003-4819-158-12-201306180-02003 | X | | | Publication Status
290 | Estruch R, Ros E, Salas-Salvado J, et al. Primary prevention of cardiovascular disease with a Mediterranean diet supplemented with extra-virgin olive oil or nuts. N Engl J Med. 2018;378(25):e34. doi:10.1056/NEJMoa1800389 | | X
291 | Estruch R, Ros E, Salas-Salvadó, et al. Primary prevention of cardiovascular disease with a Mediterranean diet. N Engl J Med. 2013;368(14):1279-1290. doi:10.1056/NEJMoa1200303 | | X
292 | Faghihnia N, Mangravite LM, Chiu S, Bergeron N, Krauss RM. Effects of dietary saturated fat on LDL subclasses and apolipoprotein CIII in men. Eur J Clin Nutr. 2012;66(11):1229-33. doi:10.1038/ejcn.2012.118 | | | | Study Duration
293 | Fahrer H, Hoeflin F, Lauterburg BH, Peheim E, Levy A, Vischer TL. Diet and fatty acids: can fish substitute for fish oil?. Clin Exp Rheumatol. 1991. 9(4):403-6. | | X | | Age of participants at intervention or exposure
294 | Fallaize R, Livingstone KM, Celis-Morales C, et al. Association between diet-quality scores, adiposity, total cholesterol and markers of nutritional status in European adults: findings from the Food4Me study. Nutrients. 2018;10(1): pii: E49. doi:10.3390/nu10010049 | X | X
295 | Farras M, Arranz S, Carrion S, et al. A functional virgin olive oil enriched with olive oil and thyme phenolic compounds improves the expression of cholesterol efflux-related genes: a randomized, crossover, controlled trial. Nutrients. 2019;11(8): pii: E1732. doi:10.3390/nu11081732 | | X | X
296 | Farras M, Castaner O, Martin-Pelaez S, et al. Complementary phenol-enriched olive oil improves HDL characteristics in hypercholesterolemic subjects. A randomized, double-blind, crossover, controlled trial. The VOHF study. Mol Nutr Food Res. 2015;59(9):1758-70. doi:10.1002/mnfr.201500030 | | | | Health Status
297 | Farvid MS, Malekshah AF, Pourshams A, et al. Dairy food intake and all-cause, cardiovascular disease, and cancer mortality: The Golestan Cohort Study. Am J Epidemiol. 2017;185(8):697-711. doi:10.1093/aje/kww139 | | X
298 | Fathi Y, Ghodrati N, Zibaeenezhad MJ, Faghih S. Kefir drink causes a significant yet similar improvement in serum lipid profile, compared with low-fat milk, in a dairy-rich diet in overweight or obese premenopausal women: A randomized controlled trial. J Clin Lipidol. 2017;11(1):136-146. doi:10.1016/j.jacl.2016.10.016 | | X
299 | Fava F, Gitau R, Griffin BA, Gibson GR, Tuohy KM, Lovegrove JA. The type and quantity of dietary fat and carbohydrate alter faecal microbiome and short-chain fatty acid excretion in a metabolic syndrome ‘at-risk’ population. Int J Obes (Lond). 2013;37(2):216-23. doi:10.1038/ijo.2012.33 | | | | Duplicate data
300 | Fazeli Moghadam E, Tadevosyan A, Fallahi E, Goodarzi R. Nutritional factors and metabolic variables in relation to the risk of coronary heart disease: a case control study in Armenian adults. Diabetes Metab Syndr. 2017;11(1):7-11. doi:10.1016/j.dsx.2016.06.013 | X
301 | Feeney EL, Barron R, Dible V, et al. Dairy matrix effects: response to consumption of dairy fat differs when eaten within the cheese matrix-a randomized controlled trial. Am J Clin Nutr. 2018;108(4):667-674. doi:10.1093/ajcn/nqy146 | | X
302 | Fernández De La Puebla RA, Carmona J, Fuentes F, et al. Response degree of cholesterol LDL to feeding in males with hypercholesterolemia according to baseline value. Medicina clinica. 2002;118(19):737- 740. | | | | Language
303 | Fernandez ML, Ballesteros MN, Cabrera RM, Saucedo S, Clark RM. Intake of two eggs per day increases plasma lutein and zeaxanthin without affecting the LDL/HDL ratio in Mexican children aged 8-12 y. FASEB journal. 2011;25. | | | | Publication Status
304 | Fernandez-Castillejo S, Rubio L, Hernaez A, et al. Determinants of HDL cholesterol efflux capacity after virgin olive oil ingestion: interrelationships with fluidity of HDL monolayer. Mol Nutr Food Res. 2017;61(12). doi:10.1002/mnfr.201700445 | | X
305 | Fernandez-Castillejo S, Valls RM, Castaner O, et al. Polyphenol rich olive oils improve lipoprotein particle atherogenic ratios and subclasses profile: a randomized, crossover, controlled trial. Mol Nutr Food Res. 2016;60(7):1544-54. doi:10.1002/mnfr.201501068 | | X | | Health Status
306 | Feuerstein JS, Bautista LT, Bjerke WS. A dietary approach for treating dyslipidemia and hyperglycemia. Current Nutrition and Food Science. 2011;7(4):271-274. | X | X
307 | Fito M, Estruch R, Salas-Salvado J, et al. Effect of the Mediterranean diet on heart failure biomarkers: a randomized sample from the PREDIMED trial. Eur J Heart Fail. 2014;16(5):543-50. doi:10.1002/ejhf.61 | | X | X
308 | Fitschen PJ, Rolfhus KR, Winfrey MR, Allen BK, Manzy M, Maher MA. Cardiovascular effects of consumption of black versus English walnuts. J Med Food. 2011;14(9):890-8. doi:10.1089/jmf.2010.0169 | | X
309 | Fleming J, Kris-Etherton P, Petersen K, Baer D. The dose-response effect of a mediterranean style diet with lean beef on lipids and lipoproteins. Circulation. 2019;139. doi:10.1161/circ.139.suppl_1.045 | | | | Publication Status
310 | Flynn MM, Reinert SE. Comparing an olive oil-enriched diet to a standard lower-fat diet for weight loss in breast cancer survivors: a pilot study. J Womens Health (Larchmt). 2010;19(6):1155-61. doi:10.1089/jwh.2009.1759 | | X
311 | Fonolla-Joya J, Reyes-Garcia R, Garcia-Martin A, Lopez-Huertas E, Munoz-Torres M. Daily Intake of Milk Enriched with n-3 Fatty AcidsOleic Acidand Calcium Improves Metabolic and Bone Biomarkers in Postmenopausal Women. J Am Coll Nutr. 2016;35(6):529-536. doi:10.1080/07315724.2014.1003114 | | X
312 | Foraker RE, Pennell M, Sprangers P, Vitolins MZ, DeGraffinreid C, Paskett ED. Effect of a low-fat or low-carbohydrate weight-loss diet on markers of cardiovascular risk among premenopausal women: a randomized trial. J Womens Health (Larchmt). 2014;23(8):675-80. doi:10.1089/jwh.2013.4638 | | X
313 | Ford PA, Jaceldo-Siegl K, Lee JW, Tonstad S. Trans fatty acid intake is related to emotional affect in the Adventist Health Study-2. Nutr Res. 2016;36(6):509-17. doi:10.1016/j.nutres.2016.01.005 | | | X
314 | Foster GD, Wyatt HR, Hill JO, et al. Weight and metabolic outcomes after 2 years on a low-carbohydrate versus low-fat diet: a randomized trial. Ann Intern Med. 2010;153(3):147-57. doi:10.7326/0003-4819-153-3-201008030-00005 | | X
315 | Frahnow T, Osterhoff MA, Hornemann S, et al. Heritability and responses to high fat diet of plasma lipidomics in a twin study. Sci Rep. 2017;7(1):3750. doi:10.1038/s41598-017-03965-6 | | X
316 | Francesco Sofi F, Cesari F, Gori AM, et al. The atherosclerotic risk profile is differently affected from fish fed with similar EPA+DHA content but different N-6/N-3 ratio: a single-blinded randomized crossover trial. Eur J Prev Cardiol. 2013. 20(1 SUPPL. 1):S116. doi:10.1177/2047487314530052 | | | | Publication Status
317 | Freitas-Simoes TM, Cofan M, Serra-Mir M, et al. Walnut supplementation for 2 years in older individuals reduces ldlcholesterol without adverse effects on adiposity. a sub-study of the walnuts and healthy aging (WAHA) study. Annals of nutrition & metabolism. 2017;71(Suppl 2):988- 989. doi:10.1159/000480486 | | | | Publication Status
318 | Fretts AM, Mozaffarian D, Siscovick DS, et al. Associations of plasma phospholipid and dietary alpha linolenic acid with incident atrial fibrillation in older adults: the Cardiovascular Health Study. J Am Heart Assoc. 2013;2(1):e003814. doi:10.1161/jaha.112.003814 | | | X
319 | Friday KE, Failor RA, Childs MT, Bierman EL. Effects of n-3 and n-6 fatty acid-enriched diets on plasma lipoproteins and apolipoproteins in heterozygous familial hypercholesterolemia. Arterioscler Thromb. 1991. 11(1):47-54. doi:10.1161/01.atv.11.1.47 | | | | Age of participants at intervention or exposure
320 | Frolich S, Lehmann N, Weyers S, et al. Association of dietary patterns with five-year degree and progression of coronary artery calcification in the Heinz Nixdorf Recall study. Nutr Metab Cardiovasc Dis. 2017;27(11):999-1007. doi:10.1016/j.numecd.2017.09.002 | | X
321 | Fuchs GJ, Farris RP, DeWier M, Hutchinson S, Strada R, Suskind RM. Effect of dietary fat on cardiovascular risk factors in infancy. Pediatrics. 1994. 93(5):756-63. | | X
322 | Fukuoka Y, Nuruki N, Amiya S, Tofuku K, Aosaki S, Tsubouchi H. Effects of a fish-based diet and administration of pure eicosapentaenoic acid on brachial-ankle pulse wave velocity in patients with cardiovascular risk factors. J Cardiol. 2014;63(3):211-7. doi:10.1016/j.jjcc.2013.08.005 | | X | | Health Status
323 | Fulgoni VL 3rd, Dreher M, Davenport AJ. Avocado consumption is associated with better diet quality and nutrient intake, and lower metabolic syndrome risk in US adults: results from the National Health and Nutrition Examination Survey (NHANES) 2001-2008. Nutr J. 2013;121. doi:10.1186/1475-2891-12-1 | X
324 | Fuller NR, Caterson ID, Sainsbury A, et al. The effect of a high-egg diet on cardiovascular risk factors in people with type 2 diabetes: the Diabetes and Egg (DIABEGG) study-a 3-mo randomized controlled trial. Am J Clin Nutr. 2015;101(4):705-13. doi:10.3945/ajcn.114.096925 | | X
325 | Fumeron F, Lamri A, Abi Khalil C, et al. Dairy consumption and the incidence of hyperglycemia and the metabolic syndrome: results from a French prospective studydata from the epidemiological study on the insulin resistance syndrome (DESIR). Diabetes Care. 2011;34(4):813-817. doi:10.2337/dc10-1772 | | X
326 | Fumeron F, Lamri A, Emery N, et al. Dairy products and the metabolic syndrome in a prospective study, DESIR. J Am Coll Nutr. 2011;30(5 Suppl 1):454s-63s. doi:10.1080/07315724.2011.10719990 | | X
327 | Furtado JD, Beqari J, Campos H. Comparison of the utility of total plasma fatty acids versus those in cholesteryl ester, phospholipidand triglyceride as biomarkers of fatty acid intake. Nutrients. 2019;11(9): pii: E2081. doi:10.3390/nu11092081 | | X | X
328 | Furtado JD, Campos H, Sumner AE, Appel LJ, Carey VJ, Sacks FM. Dietary interventions that lower lipoproteins containing apolipoprotein C-III are more effective in whites than in blacks: results of the OmniHeart trial. Am J Clin Nutr. 2010;92(4):714-22. doi:10.3945/ajcn.2009.28532 | | X
329 | Garcia A, Gutierrez JM, Fernandez S, Aparicio J, Menendez-Patterson A. Dietary intervention in a hypercholesterolemic school-aged population from Northern Spain. Rev Esp Fisiol. 1996. 52(1):49-58. | X | X
330 | Garcia-Alonso FJ, Jorge-Vidal V, Ros G, Periago MJ. Effect of consumption of tomato juice enriched with n-3 polyunsaturated fatty acids on the lipid profile, antioxidant biomarker status, and cardiovascular disease risk in healthy women. Eur J Nutr. 2012;51(4):415-24. doi:10.1007/s00394-011-0225-0 | | X
331 | Garcia-Calzon S, Martinez-Gonzalez MA, Razquin C, et al. Mediterranean diet and telomere length in high cardiovascular risk subjects from the PREDIMED-NAVARRA study. Clin Nutr. 2016;35(6):1399-1405. doi:10.1016/j.clnu.2016.03.013 | | X | X
332 | Garcia-Esquinas E, Ortola R, Banegas JR, Lopez-Garcia E, Rodriguez-Artalejo F. Dietary n-3 polyunsaturated fatty acidsfish intake and healthy ageing. Int J Epidemiol. 2019;48(6):1914-1924. doi:10.1093/ije/dyz196 | | | X
333 | Garcia-Gavilan JF, Bullo M, Canudas S, et al. Extra virgin olive oil consumption reduces the risk of osteoporotic fractures in the PREDIMED trial. Clin Nutr. 2018;37(1):329-335. doi:10.1016/j.clnu.2016.12.030 | | | X
334 | Garcia-Rios A, Alcala-Diaz JF, Gomez-Delgado F, et al. Beneficial effect of CETP gene polymorphism in combination with a Mediterranean diet influencing lipid metabolism in metabolic syndrome patients: CORDIOPREV study. Clin Nutr. 2018;37(1):229-234. doi:10.1016/j.clnu.2016.12.011 | | X | | Health Status
335 | Garcia-Rios A, Gomez-Delgado FJ, Delgado-Lista FJ, et al. Beneficial effect of CETP gene polymorphism rs3764261 in combination with a Mediterranean diet on lipid metabolism in metabolic syndrome. Atherosclerosis. 2014. 235(2):e115. doi:10.1016/j.atherosclerosis.2014.05.314 | | | | Publication Status
336 | Gaskins AJ, Rovner AJ, Mumford SL, et al. Adherence to a Mediterranean diet and plasma concentrations of lipid peroxidation in premenopausal women. Am J Clin Nutr. 2010;92(6):1461-7. doi:10.3945/ajcn.110.000026 | | X | X
337 | Gebauer SK, Destaillats F, Dionisi F, Krauss RM, Baer DJ. Vaccenic acid and trans fatty acid isomers from partially hydrogenated oil both adversely affect LDL cholesterol: a double-blind, randomized controlled trial. Am J Clin Nutr. 2015;102(6):1339-46. doi:10.3945/ajcn.115.116129 | | X
338 | Georgiopoulos G, Karatzi K, Euthimiou E, et al. Association of macronutrient consumption with arterial aging in adults without clinically overt cardiovascular disease: a 5-year prospective cohort study. Eur J Nutr. 2019;58(6):2305-2314. doi:10.1007/s00394-018-1781-3 | | | X
339 | Gepner Y, Shelef I, Schwarzfuchs D, et al. Effect of distinct lifestyle interventions on mobilization of fat storage pools: CENTRAL Magnetic Resonance Imaging Randomized Controlled Trial. Circulation. 2018;137(11):1143-1157. doi:10.1161/circulationaha.117.030501 | | X | X
340 | Ghotboddin Mohammadi S, Mirmiran P, Bahadoran Z, Mehrabi Y, Azizi F. The association of dairy intake with metabolic syndrome and its components in adolescents: Tehran Lipid and Glucose Study. Int J Endocrinol Metab. 2015;13(3):e25201. doi:10.5812/ijem.25201v2 | X | X
341 | Gillingham LG, Gustafson JA, Han SY, Jassal DS, Jones PJ. High-oleic rapeseed (canola) and flaxseed oils modulate serum lipids and inflammatory biomarkers in hypercholesterolaemic subjects. Br J Nutr. 2011;105(3):417-27. doi:10.1017/s0007114510003697 | | | | Health Status
342 | Gillingham MB, Elizondo G, Behrend A, et al. Higher dietary protein intake preserves lean body mass, lowers liver lipid deposition, and maintains metabolic control in participants with long-chain fatty acid oxidation disorders. J Inherit Metab Dis. 2019;42(5):857-869. doi:10.1002/jimd.12155 | | X | X
343 | Giovannini M, Bellu R, Ortisi MT, Incerti P, Riva E. Cholesterol and lipoprotein levels in Milanese children: relation to nutritional and familial factors. J Am Coll Nutr. 1992. 11 Suppl28s-31s. doi:10.1080/07315724.1992.10737980 | X | X
344 | Gladine C, Combe N, Vaysse C, et al. Optimized rapeseed oil enriched with healthy micronutrients: a relevant nutritional approach to prevent cardiovascular diseases. Results of the Optim’Oils randomized intervention trial. J Nutr Biochem. 2013;24(3):544-9. doi:10.1016/j.jnutbio.2012.02.003 | | X
345 | Glassman M, Spark A, Berezin S, Schwarz S, Medow M, Newman LJ. Treatment of type IIa hyperlipidemia in childhood by a simplified American Heart Association diet and fiber supplementation. Am J Dis Child. 1990. 144(9):973-6. doi:10.1001/archpedi.1990.02150330033016 | | X
346 | Gold K, Wong N, Tong A, et al. Serum apolipoprotein and lipid profile effects of an oat-bran-supplementedlow-fat diet in children with elevated serum cholesterol. Ann N Y Acad Sci. 1991. 623:429-31. doi:10.1111/j.1749-6632.1991.tb43758.x | | X
347 | Gomez de la Camara A, De Andres Esteban E, Urrutia Cuchi G, et al. Variability of nutrients intakelipid profile and cardiovascular mortality among geographical areas in Spain: The DRECE study. Geospat Health. 2017;12(2):524. doi:10.4081/gh.2017.524 | | X
348 | Gomez-Delgado F, Alcala-Diaz JF, Garcia-Rios A, et al. Polymorphism at the TNF-alpha gene interacts with Mediterranean diet to influence triglyceride metabolism and inflammation status in metabolic syndrome patients: From the CORDIOPREV clinical trial. Mol Nutr Food Res. 2014;58(7):1519-27. doi:10.1002/mnfr.201300723 | | X | | Health Status
349 | Gomez-Marin B, Gomez-Delgado F, Lopez-Moreno J, et al. Long-term consumption of a Mediterranean diet improves postprandial lipemia in patients with type 2 diabetes: the Cordioprev randomized trial. Am J Clin Nutr. 2018;108(5):963-970. doi:10.1093/ajcn/nqy144 | | | | Health Status
350 | Gonciulea AR, Sellmeyer D. The effect of dietary protein source on serum lipids. Endocrine reviews. 2015;36(Suppl 2). | | | | Publication Status
351 | Gonzalez-Requejo A, Sanchez-Bayle M, Baeza J, et al. Relations between nutrient intake and serum lipid and apolipoprotein levels. J Pediatr. 1995. 127(1):53-7. doi:10.1016/s0022-3476(95)70256-3 | X
352 | Gopinath B, Flood VM, Burlutksy G, Mitchell P. Consumption of nuts and risk of total and cause-specific mortality over 15 years. Nutr Metabol Cardiovasc Dis. 2015;25(12):1125-1131. doi:10.1016/j.numecd.2015.09.006 | | X
353 | Gorczyca D, Pasciak M, Szponar B, Gamian A, Jankowski A. An impact of the diet on serum fatty acid and lipid profiles in Polish vegetarian children and children with allergy. Eur J Clin Nutr. 2011;65(2):191-5. doi:10.1038/ejcn.2010.231 | X | X
354 | Gossell-Williams M, Hyde C, Hunter T, et al. Improvement in HDL cholesterol in postmenopausal women supplemented with pumpkin seed oil: pilot study. Climacteric. 2011;14(5):558-64. doi:10.3109/13697137.2011.563882 | | X
355 | Goulooze SC, Cohen AF, Rissmann R. Lomitapide. Br J Clin Pharmacol. 2015;80(2):179-81. doi:10.1111/bcp.12612 | X | X
356 | Grabovac I, Hochfellner L, Rieger M, et al. Impact of Austria’s 2009 trans fatty acids regulation on all-causecardiovascular and coronary heart disease mortality. Eur J Public Health. 2018;28(Suppl 2):4-9. doi:10.1093/eurpub/cky147 | | X
357 | Graff SK, Mario FM, Magalhaes JA, Moraes RS, Spritzer PM. Saturated fat intake is related to heart rate variability in women with polycystic ovary syndrome. Ann Nutr Metab. 2017;71(3-4):224-233. doi:10.1159/000484325 | X | | X
358 | Grasgruber P, Sebera M, Hrazdira E, Hrebickova S, Cacek J. Food consumption and the actual statistics of cardiovascular diseases: an epidemiological comparison of 42 European countries. Food Nutr Res. 2016;60:31694. doi:10.3402/fnr.v60.31694 | X | X
359 | Greene CM, Zern TL, Wood RJ, et al. Maintenance of the LDL cholesterol: HDL cholesterol ratio in an elderly population given a dietary cholesterol challenge. J Nutr. 2005. 135(12):2793-8. doi:10.1093/jn/135.12.2793 | | | | Age of participants at intervention or exposure
360 | Greupner T, Kutzner L, Nolte F, et al. Effects of a 12-week high-alpha-linolenic acid intervention on EPA and DHA concentrations in red blood cells and plasma oxylipin pattern in subjects with a low EPA and DHA status. Food Funct. 2018;9(3):1587-1600. doi:10.1039/c7fo01809f | X | | X
361 | Griffin BA, Walker CG, Jebb SA, et al. APOE4 genotype exerts greater benefit in lowering plasma cholesterol and apolipoprotein b than wild type (E3/E3), after replacement of dietary saturated fats with low glycaemic index carbohydrates. Nutrients. 2018;10(10): pii: E1524. doi:10.3390/nu10101524 | | X
362 | Griffin LE, Djuric Z, Angiletta CJ, et al. A Mediterranean diet does not alter plasma trimethylamine N-oxide concentrations in healthy adults at risk for colon cancer. Food Funct. 2019;10(4):2138-2147. doi:10.1039/c9fo00333a | | | X
363 | Griffith KA, Royak-Schaler R, Nesbitt K, et al. A culturally specific dietary plan to manage weight gain among African American breast cancer survivors: a feasibility study. Nutr Health. 2012;21(2):97-105. doi:10.1177/0260106012459938 | | X
364 | Grimaldi M, Ciano O, Manzo M, et al. Intensive dietary intervention promoting the Mediterranean diet in people with high cardiometabolic risk: a non-randomized study. Acta Diabetol. 2018;55(3):219-226. doi:10.1007/s00592-017-1078-7 | | X
365 | Grosso G, Stepaniak U, Micek A, et al. A Mediterranean-type diet is associated with better metabolic profile in urban Polish adults: results from the HAPIEE study. Metabolism. 2015;64(6):738-46. doi:10.1016/j.metabol.2015.02.007 | X
366 | Grygiel-Górniak B, Kaczmarek E, Mosor M, Przysławski J, Nowak J. The gene-diet associations in postmenopausal women with newly diagnosed dyslipidemia. J Nutr Health Aging. 2017;21(9):1031-1037. doi:10.1007/s12603-017-0877-4 | X | X
367 | Grytten E, Laupsa Borge J, Dankel S, et al. Effects of omega-3 and omega-6 fatty acids on lipids and apolipoproteins, glycemic response and endothelial function: a randomized double-blind crossover trial. Obesity facts. 2019;12260. doi:10.1159/000489691 | | | | Publication Status
368 | Guallar-Castillon P, Rodriguez-Artalejo F, Lopez-Garcia E, et al. Consumption of fried foods and risk of coronary heart disease: Spanish cohort of the European Prospective Investigation into Cancer and Nutrition study. BMJ. 2012;344e363. doi:10.1136/bmj.e363 | | X
369 | Guallar-Castillon P, Rodriguez-Artalejo F, Tormo MJ, et al. Major dietary patterns and risk of coronary heart disease in middle-aged persons from a Mediterranean country: the EPIC-Spain cohort study. Nutr Metab Cardiovasc Dis. 2012;22(3):192-9. doi:10.1016/j.numecd.2010.06.004 | | X
370 | Guasch-Ferre M, Bullo M, Martinez-Gonzalez MA, et al. Frequency of nut consumption and risk of total mortality in the predimed study. Annals of nutrition and metabolism. 2013. 62(Suppl 2):17- 18. doi:10.1159/000351281 | | | | Publication Status
371 | Guasch-Ferre M, Bullo M, Martinez-Gonzalez MA, et al. Frequency of nut consumption and mortality risk in the PREDIMED nutrition intervention trial. BMC Med. 2013;11:164. doi:10.1186/1741-7015-11-164 | | X
372 | Guasch-Ferre M, Zong G, Willett WC, et al. Associations of monounsaturated fatty acids from plant and animal sources with total and cause-specific mortality in two US prospective cohort studies. Circ Res. 2019;124(8):1266-1275. doi:10.1161/circresaha.118.313996 | X
373 | Guay V, Lamarche B, Charest A, Tremblay AJ, Couture P. Effect of short-term low- and high-fat diets on low-density lipoprotein particle size in normolipidemic subjects. Metabolism. 2012;61(1):76-83. doi:10.1016/j.metabol.2011.06.002 | | | | Study Duration
374 | Guevara-Cruz M, Flores-Lopez AG, Aguilar-Lopez M, et al. Improvement of lipoprotein profile and metabolic endotoxemia by a lifestyle intervention that modifies the gut microbiota in subjects with metabolic syndrome. J Am Heart Assoc. 2019;8(17):e012401. doi:10.1161/jaha.119.012401 | | X
375 | Guillaume M, Lapidus L, Lambert A. Differences in associations of familial and nutritional factors with serum lipids between boys and girls: The Luxombourg Child Study. Am J Clin Nutr. 2000. 72(2):384-388. | X
376 | Gulati S, Misra A, Pandey RM, Bhatt SP, Saluja S. Effects of pistachio nuts on body composition, metabolic, inflammatory and oxidative stress parameters in Asian Indians with metabolic syndrome: a 24-wk, randomized control trial. Nutrition. 2014;30(2):192-7. doi:10.1016/j.nut.2013.08.005 | | X | | Country
377 | Gulesserian T, Widhalm K. Effect of a rapeseed oil substituting diet on serum lipids and lipoproteins in children and adolescents with familial hypercholesterolemia. J Am Coll Nutr. 2002;21(2):103-8. doi:10.1080/07315724.2002.10719201 | | X | | Health Status
378 | Gulseth HL, Gjelstad IM, Tierney AC, et al. Dietary fat modifications and blood pressure in subjects with the metabolic syndrome in the LIPGENE dietary intervention study. Br J Nutr. 2010;104(2):160-3. doi:10.1017/s0007114510000565 | | | | Duplicate data
379 | Güneş Ö, Soylu M, İnanç N, et al. Relationship between red blood cell membrane fatty acid composition and dietary fatty acids level in obese adolescents with/without metabolic syndrome. Progress in Nutrition. 2018;20(4):648-658. doi:10.23751/pn.v20i4.6039 | X | X
380 | Guo Z, Miura K, Turin TC, Hozawa A, et al. Relationship of the polyunsaturated to saturated fatty acid ratio to cardiovascular risk factors and metabolic syndrome in Japanese: the INTERLIPID study. J Atheroscler Thromb. 2010;17(8):777-84. doi:10.5551/jat.4135 | X
381 | Gustavsson J, Mehlig K, Leander K, et al. FTO gene variationmacronutrient intake and coronary heart disease risk: a gene-diet interaction analysis. Eur J Nutr. 2016;55(1):247-55. doi:10.1007/s00394-015-0842-0 | X
382 | Guzel O, Yilmaz U, Uysal U, Arslan N. The effect of olive oil-based ketogenic diet on serum lipid levels in epileptic children. Neurol Sci. 2016;37(3):465-70. doi:10.1007/s10072-015-2436-2 | X | | | Health Status
383 | Guzman MA. Diet and chronic diseases: INCAP studies of atherosclerosis and coronary heart disease. Food Nutr Bull. 2010;31(1):141-51. doi:10.1177/156482651003100114 | X
384 | Gwynne M, Mounsey A. Mediterranean diet: higher fat but lower risk. J Fam Pract. 2013;62(12):745-748. | X
385 | Ha K, Joung H, Song Y. Inadequate fat or carbohydrate intake was associated with an increased incidence of type 2 diabetes mellitus in Korean adults: a 12-year community-based prospective cohort study. Diabetes Res Clin Pract. 2019;148254-261. doi:10.1016/j.diabres.2019.01.024 | | | X
386 | Hajiluian G, Abbasalizad Farhangi M, Jahangiry L. Mediterranean dietary pattern and VEGF +405 G/C gene polymorphisms in patients with metabolic syndrome: an aspect of gene-nutrient interaction. PLoS One. 2017;12(2):e0171637. doi:10.1371/journal.pone.0171637 | X
387 | Halliday TM, Polsky S, Schoen JA, et al. Comparison of surgical versus diet-induced weight loss on appetite regulation and metabolic health outcomes. Physiol Rep. 2019;7(7):e14048. doi:10.14814/phy2.14048 | | X
388 | Hammoud A, Gastaldi M, Maillot M, et al. APOB-516 T allele homozygous subjects are unresponsive to dietary changes in a three-month primary intervention study targeted to reduce fat intake. Genes Nutr. 2010;5(1):29-37. doi:10.1007/s12263-009-0155-0 | | X
389 | Hamulka J, Glabska D, Guzek D, Bialkowska A, Sulich A. Intake of saturated fatty acids affects atherogenic blood properties in young, caucasian, overweight women even without influencing blood cholesterol. Int J Environ Res Public Health. 2018;15(11): pii: E2530. doi:10.3390/ijerph15112530 | X
390 | Hansen CK, Klingenberg L, Larsen LB, Lorenzen JK, Sorensen KV, Astrup A. The effect of UHT-processed dairy milk on cardio-metabolic risk factors. Eur J Clin Nutr. 2017;71(12):1463-1466. doi:10.1038/ejcn.2017.22 | | X
391 | Hansen-Krone IJ, Enga KF, Njolstad I, Hansen JB, Braekkan SK. Heart healthy diet and risk of myocardial infarction and venous thromboembolism. The Tromso Study. Thromb Haemost. 2012;108(3):554-60. doi:10.1160/th11-11-0818 | | X
392 | Hansen-Krone IJ, Enga KF, Sudduth-Klinger JM, et al. High fish plus fish oil intake is associated with slightly reduced risk of venous thromboembolism: the Tromso Study. J Nutr. 2014;144(6):861-7. doi:10.3945/jn.113.189548 | | X
393 | Hansson P, Holven KB, Oyri LKL, et al. Sex differences in postprandal responses to different dairy products on lipoprotein subclasses: a randomized controlled cross-over trial. Br J Nutr. 2019;122(7):780-789. doi:10.1017/s0007114519001429 | X | | X
394 | Haraldsdottir A, Torfadottir JE, Valdimarsdottir UA, et al. Fish and fish-liver oil consumption in adolescence and midlife and risk of CHD in older women. Public Health Nutr. 2016;19(2):318-25. doi:10.1017/s1368980015001020 | | X
395 | Haring B, Selvin E, Liang M, et al. Dietary protein sources and risk for incident chronic kidney disease: results from the Atherosclerosis Risk in Communities (ARIC) Study. J Ren Nutr. 2017;27(4):233-242. doi:10.1053/j.jrn.2016.11.004 | | X | X
396 | Harnden KE, Frayn KN, Hodson L. Dietary Approaches to Stop Hypertension (DASH) diet: applicability and acceptability to a UK population. J Hum Nutr Diet. 2010;23(1):3-10. doi:10.1111/j.1365-277X.2009.01007.x | | X | X
397 | Harreiter J, Simmons D, Desoye G, et al. Nutritional lifestyle intervention in obese pregnant women, including lower carbohydrate intake, is associated with increased maternal free fatty acids, 3-beta-Hydroxybutyrate, and fasting glucose concentrations: a secondary factorial analysis of the European Multicenter, Randomized Controlled DALI Lifestyle Intervention Trial. Diabetes Care. 2019;42(8):1380-1389. doi:10.2337/dc19-0418 | | X | X
398 | Harris CP, von Berg A, Berdel D, et al. Association of dietary fatty acids with blood lipids is modified by physical activity in adolescents: results from the GINIplus and LISA birth cohort studies. Nutrients. 2018;10(10). doi:10.3390/nu10101372 | X
399 | Harris M, Fryda L, Hutchins A. The impact of virgin coconut and safflower oils on lipids and cytokines in postmenopausal women. FASEB journal. 2015;29(Suppl 1). | | | | Publication Status
400 | Hart K, Barr S, Reeves S, Sharp K, Jeanes Y. Suboptimal dietary intake is associated with cardiometabolic risk factors in women with polycystic ovary syndrome. Nutrition & Dietetics. 2016;73(2):177-183. doi:10.1111/1747-0080.12188 | | X
401 | Hartiala J, Gilliam E, Vikman S, Campos H, Allayee H. Association of PLA2G4A with myocardial infarction is modulated by dietary PUFAs. Am J Clin Nutr. 2012;95(4):959-65. doi:10.3945/ajcn.111.032094 | X
402 | Haruna M, Shiraishi M, Matsuzaki M, Yatsuki Y, Yeo S. Effect of tailored dietary guidance for pregnant women on nutritional status: A double-cohort study. Matern Child Nutr. 2017;13(4): doi:10.1111/mcn.12391 | | | X
403 | Harvey CJDC, Schofield GM, Zinn C, Thornley SJ, Crofts C, Merien FLR. Low-carbohydrate diets differing in carbohydrate restriction improve cardiometabolic and anthropometric markers in healthy adults: a randomised clinical trial. PeerJ. 2019;2019. 5;7:e6273. doi:10.7717/peerj.6273 | | X
404 | Hashemi R, Mehdizadeh Khalifani A, Rahimlou M, Manafi M. Comparison of the effect of Dietary Approaches to Stop Hypertension diet and American Diabetes Association nutrition guidelines on lipid profiles in patients with type 2 diabetes: a comparative clinical trial. Nutr Diet. 2019;77(2):204-211. doi:10.1111/1747-0080.12543 | | | | Health Status
405 | Haufe S, Utz W, Engeli S, et al. Left ventricular mass and function with reduced-fat or reduced-carbohydrate hypocaloric diets in overweight and obese subjects. Hypertension. 2012. 59(1):70- 75. doi:10.1161/hypertensionaha.111.178616 | | X
406 | Hayman LL. The Dietary Intervention Study in Children (DISC): progress and prospects for primary prevention. Prog Cardiovasc Nurs. 2003. 18(1):4- 5. | X
407 | Heine-Broring RC, Brouwer IA, Proenca RV, et al. Intake of fish and marine n-3 fatty acids in relation to coronary calcification: the Rotterdam Study. Am J Clin Nutr. 2010;91(5):1317-23. doi:10.3945/ajcn.2009.28416 | | | X
408 | Helal O, Berrougui H, Loued S, Khalil A. Extra-virgin olive oil consumption improves the capacity of HDL to mediate cholesterol efflux and increases ABCA1 and ABCG1 expression in human macrophages. Br J Nutr. 2013;109(10):1844-55. doi:10.1017/s0007114512003856 | X | X
409 | Hellstrand S, Ericson U, Schulz CA, et al. Genetic susceptibility to dyslipidemia and incidence of cardiovascular disease depending on a diet quality index in the Malmö diet and cancer cohort. Genes Nutr. 2016;11(1). doi:10.1186/s12263-016-0536-0 | | X
410 | Henning SM, Yang J, Woo SL, et al. Hass avocado inclusion in a weight-loss diet supported weight loss and altered gut microbiota: a 12-week randomized, parallel-controlled trial. Curr Dev Nutri. 2019;3(8):nzz068. doi:10.1093/cdn/nzz068 | | X
411 | Heraclides A, Mishra GD, Hardy RJ, et al. Dairy intake, blood pressure and incident hypertension in a general British population: the 1946 birth cohort. Eur J Nutr. 2012;51(5):583-591. doi:10.1007/s00394-011-0242-z | | X
412 | Hermansen K, Gregersen S, Larsen MK, Bjoernshave A, Larsen MB. Beneficial effects of medium-chain saturated dairy fat on the body composition of abdominal obese subjects (dairyhealth): a 12-week, randomized, double-blinded, intervention study. Diabetes. 2015. 64A208- A209. doi:10.2337/db15742931 | | | | Publication Status
413 | Hernaez A, Castaner O, Elosua R, et al. Mediterranean diet improves high-density lipoprotein function in high-cardiovascular-risk individuals: a randomized controlled trial. Circulation. 2017;135(7):633-643. doi:10.1161/circulationaha.116.023712 | | X
414 | Hernaez A, Castaner O, Goday A, et al. The Mediterranean diet decreases LDL atherogenicity in high cardiovascular risk individuals: a randomized controlled trial. Mol Nutr Food Res. 2017;61(9). doi:10.1002/mnfr.201601015 | | X
415 | Hernaez A, Fernandez-Castillejo S, Farras M, et al. Olive oil polyphenols enhance high-density lipoprotein function in humans: a randomized controlled trial. Arterioscler Thromb Vasc Biol. 2014;34(9):2115-9. doi:10.1161/atvbaha.114.303374 | | X
416 | Hernaez A, Remaley AT, Farras M, et al. Olive oil polyphenols decrease LDL concentrations and LDL atherogenicity in men in a randomized controlled trial. J Nutr. 2015;145(8):1692-7. doi:10.3945/jn.115.211557 | | X
417 | Hernaez A, Sanllorente A, Castaner O, et al. Increased consumption of virgin olive oil, nuts, legumes, whole grains, and fish promotes HDL Functions in humans. Mol Nutr Food Res. 2019;63(6):e1800847. doi:10.1002/mnfr.201800847 | | | X
418 | Hernandez TL, Sutherland JP, Wolfe P, et al. Lack of suppression of circulating free fatty acids and hypercholesterolemia during weight loss on a high-fat, low-carbohydrate diet. Am J Clin Nutr. 2010;91(3):578-85. doi:10.3945/ajcn.2009.27909 | | X
419 | Hernandez-Alonso P, Salas-Salvado J, Baldrich-Mora M, Mallol R, Correig X, Bullo M. Effect of pistachio consumption on plasma lipoprotein subclasses in pre-diabetic subjects. Nutr Metab Cardiovasc Dis. 2015;25(4):396-402. doi:10.1016/j.numecd.2015.01.013 | | X | X
420 | Hernandez-Alonso P, Salas-Salvado J, Baldrich-Mora M, Mallol R, Correig X, Bullo M. Regular consumption of pistachio modulates plasma lipoprotein subclasses in pre-diabetic subjects. Obesity facts. 2015. 8(Suppl 1):872- 73. doi:10.1159/000382140 | | | | Publication Status
421 | Hernandez-Alonso P, Salas-Salvado J, Ruiz-Canela M, et al. High dietary protein intake is associated with an increased body weight and total death risk. Clin Nutr. 2016;35(2):496-506. doi:10.1016/j.clnu.2015.03.016 | | X
422 | Herron KL, Lofgren IE, Sharman M, Volek JS, Fernandez ML. High intake of cholesterol results in less atherogenic low-density lipoprotein particles in men and women independent of response classification. Metabolism. 2004. 53(6):823-30. doi:10.1016/j.metabol.2003.12.030 | | X
423 | Herron KL, Vega-Lopez S, Conde K, et al. Pre-menopausal women, classified as hypo- or hyperresponders, do not alter their LDL/HDL ratio following a high dietary cholesterol challenge. J Am Coll Nutr. 2002;21(3):250-8. doi:10.1080/07315724.2002.10719218 | | | | Age of participants at intervention or exposure
424 | Herron KL, Vega-Lopez S, Conde K, Ramjiganesh T, Shachter NS, Fernandez ML. Men classified as hypo- or hyperresponders to dietary cholesterol feeding exhibit differences in lipoprotein metabolism. J Nutr. 2003. 133(4):1036-42. doi:10.1093/jn/133.4.1036 | | X | | Age of participants at intervention or exposure
425 | Hill AM, Zahradka P, Coates AM, Howe PRC, Taylor CG, Buckley JD. A 12-week randomised controlled trial to evaluate effects of dietary pulse consumption on cardiovascular disease risk factors. FASEB journal. 2017;31(Suppl 1) | | | | Publication Status
426 | Hirahatake KM, Jiang L, Wong ND, et al. Diet quality and cardiovascular disease risk in postmenopausal women with type 2 diabetes mellitus: The Women’s Health Initiative. J Am Heart Assoc. 2019;8(19):e013249. doi:10.1161/jaha.119.013249 | | X | | Health Status
427 | Hiraoka-Yamamoto J, Ikeda K, Negishi H, et al. Serum lipid effects of a monounsaturated (palmitoleic) fatty acid-rich diet based on macadamia nuts in healthy, young japanese women. Clin Exp Pharmacol Physiol. 2013;31(Suppl 2):S37-8. doi:10.1111/j.1440-1681.2004.04121.x | | | | Study Duration
428 | Hirowatari Y, Manita D, Kamachi K, Tanaka A. Effect of dietary modification by calorie restriction on cholesterol levels in lipoprotein(a) and other lipoprotein classes. Annals of Clinical Biochemistry. 2017;54(5):567-576. doi:10.1177/0004563216672247 | | X
429 | Hisamatsu T, Miura K, Ohkubo T, et al. High long-chain n-3 fatty acid intake attenuates the effect of high resting heart rate on cardiovascular mortality risk: a 24-year follow-up of Japanese general population. J Cardiol. 2014;64(3):218-24. doi:10.1016/j.jjcc.2014.01.005 | | | | Duplicate data
430 | Hjerpsted J, Leedo E, Tholstrup T. Cheese intake in large amounts lowers LDL-cholesterol concentrations compared with butter intake of equal fat content. Am J Clin Nutr. 2011;94(6):1479-84. doi:10.3945/ajcn.111.022426 | | X
431 | Hjerpsted JB, Dragsted LO, Tholstrup T. Cheese intake lowers plasma cholesterol concentrations without increasing bile acid excretion. Journal of Nutrition and Intermediary Metabolism. 2016;312-17. doi:10.1016/j.jnim.2015.11.002 | | X
432 | Hlebowicz J, Persson M, Gullberg B, et al. Food patternsinflammation markers and incidence of cardiovascular disease: the Malmo Diet and Cancer study. J Intern Med. 2011;270(4):365-76. doi:10.1111/j.1365-2796.2011.02382.x | | X
433 | Hlebowicz J, Persson M, Gullberg B, et al. Food patternsinflammation markers and incidence of cardiovascular disease: The Malmö Diet and Cancer study. Journal of Internal Medicine. 2011;270(4):365-376. doi:10.1111/j.1365-2796.2011.02382.x | X | X
434 | Hoenselaar R. Saturated fat and cardiovascular disease: the discrepancy between the scientific literature and dietary advice. Nutrition. 2012;28(2):118-23. doi:10.1016/j.nut.2011.08.017 | X
435 | Hoevenaar-Blom MP, Nooyens AC, Kromhout D, et al. Mediterranean style diet and 12-year incidence of cardiovascular diseases: the EPIC-NL cohort study. PLoS One. 2012;7(9):e45458. doi:10.1371/journal.pone.0045458 | | X
436 | Holloway CJ, Cochlin LE, Emmanuel Y, et al. A high-fat diet impairs cardiac high-energy phosphate metabolism and cognitive function in healthy human subjects. Am J Clin Nutr. 2011;93(4):748-55. doi:10.3945/ajcn.110.002758 | | X
437 | Holme I, Retterstol K, Norum KR, Hjermann I. Lifelong benefits on myocardial infarction mortality: 40-year follow-up of the randomized Oslo diet and antismoking study. J Intern Med. 2016;280(2):221-7. doi:10.1111/joim.12485 | | X
438 | Hooshmand F, Asghari G, Yuzbashian E, Mahdavi M, Mirmiran P, Azizi F. Modified Healthy Eating Index and incidence of metabolic syndrome in children and adolescents: Tehran Lipid and Glucose Study. J Pediatr. 2018;197134-139.e2. doi:10.1016/j.jpeds.2018.01.080 | | X
439 | Hoppu U, Isolauri E, Koskinen P, Laitinen K. Diet and blood lipids in 1-4 year-old children. Nutr Metab Cardiovasc Dis. 2013;23(10):980-6. doi:10.1016/j.numecd.2012.10.007 | X | X
440 | Horowitz JF, Ortega JF, Hinko A, Li M, Nelson RK, Mora-Rodriguez R. Changes in markers for cardio-metabolic disease risk after only 1-2 weeks of a high saturated fat diet in overweight adults. PLoS One. 2018;13(6):e0198372. doi:10.1371/journal.pone.0198372 | X
441 | Hoscan Y, Yigit F, Muderrisoglu H. Adherence to Mediterranean diet and its relation with cardiovascular diseases in Turkish population. Int J Clin Exp Med. 2015;8(2):2860-6. | | X
442 | Hosseini-Esfahani F, Esfandiar Z, Mirmiran P, Daneshpour MS, Ghanbarian A, Azizi F. The interaction of cholesteryl ester transfer protein gene variations and diet on changes in serum lipid profiles. Eur J Clin Nutr. 2019;73(9):1291-1298. doi:10.1038/s41430-019-0397-x | X | | X
443 | Hosseini-Esfahani F, Mirmiran P, Koochakpoor G, Daneshpour MS, Guity K, Azizi F. Some dietary factors can modulate the effect of the zinc transporters 8 polymorphism on the risk of metabolic syndrome. Sci Rep. 2017;7(1):1649. doi:10.1038/s41598-017-01762-9 | | | X
444 | Hosseinpour-Niazi S, Mirmiran P, Hosseini-Esfahani F, Azizi F. Is the metabolic syndrome inversely associates with butternon-hydrogenated- and hydrogenated-vegetable oils consumption: Tehran Lipid and Glucose study. Diabetes Res Clin Pract. 2016;11220-29. doi:10.1016/j.diabres.2015.11.008 | | | X
445 | Hostmark AT, Lunde MSH, Hjellset VT. Short communication: Daily intake of 125 g of cheese for 2 weeks did not alter amount or distribution of serum lipids or desaturase indexes in healthy adults in an exploratory pilot study. J Dairy Sci. 2018;101(11):9625-9629. doi:10.3168/jds.2018-14635 | | X
446 | Hshieh TT, Petrone AB, Gaziano JM, Djousse L. Nut consumption and risk of mortality in the Physicians’ Health Study. Am J Clin Nutr. 2015;101(2):407-12. doi:10.3945/ajcn.114.099846 | | X
447 | Htun NC, Suga H, Imai S, Shimizu W, Takimoto H. Food intake patterns and cardiovascular risk factors in Japanese adults: analyses from the 2012 National Health and nutrition surveyJapan. Nutr J. 2017;16(1):61. doi:10.1186/s12937-017-0284-z | X
448 | Hu EA, Steffen LM, Coresh J, Appel LJ, Rebholz CM. Adherence to the Healthy Eating Index-2015 and Other Dietary Patterns May Reduce Risk of Cardiovascular DiseaseCardiovascular Mortalityand All-Cause Mortality. J Nutr. 2019;150(2):312-321. doi:10.1093/jn/nxz218 | | X
449 | Hu P, Li Y, Campos H. Fried food intake and risk of nonfatal acute myocardial infarction in the Costa Rica Heart Study. PLoS One. 2018;13(2):e0192960. doi:10.1371/journal.pone.0192960 | X
450 | Hu T, Stuchlik P, Yao L, et al. Adherence to low carbohydrate and low fat diets in relation to weight loss and cardiovascular risk factor reduction. Circulation. 2015;131:AMP26 | | | | Publication Status
451 | Hu XF, Singh K, Kenny TA, Chan HM. Prevalence of heart attack and stroke and associated risk factors among Inuit in Canada: A comparison with the general Canadian population. Int J Hyg Environ Health. 2019;222(2):319-326. doi:10.1016/j.ijheh.2018.12.003 | X
452 | Huang X, Gong R, Lin J, Li R, Xiao L, Duan W, Fang D. Effects of lipoprotein lipase gene variationsa high-carbohydrate low-fat diet, and gender on serum lipid profiles in healthy Chinese Han youth. Biosci Trends. 2011;5(5):198-204. | X | X
453 | Huffman KM, Hawk VH, Henes ST, et al. Exercise effects on lipids in persons with varying dietary patterns-does diet matter if they exercise? Responses in Studies of a Targeted Risk Reduction Intervention through Defined Exercise I. Am Heart J. 2012;164(1):117-24. doi:10.1016/j.ahj.2012.04.014 | | X
454 | Huhn S, Masouleh SK, Villringer A, Witte AV. Components of a Mediterranean diet and their impact on cognitive functions in aging. Front Aging Neurosci. 2015;7:132. doi:10.3389/fnagi.2015.00132 | X
455 | Hutchins AM, Brown BD, Cunnane SC, Domitrovich SG, Adams ER, Bobowiec CE. Daily flaxseed consumption improves glycemic control in obese men and women with pre-diabetes: a randomized study. Nutr Res. 2013;33(5):367-75. doi:10.1016/j.nutres.2013.02.012 | | X | X
456 | Iannotti LL, Lutter CK, Waters WF, et al. Eggs early in complementary feeding increase choline pathway biomarkers and DHA: a randomized controlled trial in Ecuador. Am J Clin Nutr. 2017;106(6):1482-1489. doi:10.3945/ajcn.117.160515 | | X | X
457 | Iggman D, Birgisdottir B, Ramel A, Hill J, Thorsdottir I. Differences in cow’s milk composition between Iceland and the other Nordic countries and possible connections to public health. Scandinavian Journal of Nutrition. 2003. 47(4):194-198. | | | X
458 | Iggman D, Gustafsson IB, Berglund L, Vessby B, Marckmann P, Riserus U. Replacing dairy fat with rapeseed oil causes rapid improvement of hyperlipidaemia: a randomized controlled study. J Intern Med. 2011;270(4):356-64. doi:10.1111/j.13652796.2011.02383.x | | | | Health Status
459 | Ikem E, Halldorsson TI, Birgisdottir BE, Rasmussen MA, Olsen SF, Maslova E. Dietary patterns and the risk of pregnancy-associated hypertension in the Danish National Birth Cohort: a prospective longitudinal study. BJOG. 2019;126(5):663-673. doi:10.1111/1471-0528.15593 | | X
460 | Imaizumi T, Ando M, Nakatochi M, et al. Effect of dietary energy and polymorphisms in BRAP and GHRL on obesity and metabolic traits. Obes Res Clin Pract. 2018;12(Suppl 2):39-48. doi:10.1016/j.orcp.2016.05.004 | | X
461 | Imamura F, Lemaitre RN, King IB, et al. Long-chain monounsaturated Fatty acids and incidence of congestive heart failure in 2 prospective cohorts. Circulation. 2013;127(14):1512-21, 1521e1-18. doi:10.1161/circulationaha.112.001197 | | X
462 | Imran M, Anjum FM, Butt MS, Chatha ZA. Incorporation of nutritionally important fatty acids into eggs and evaluation of “Bio-Omega-3” eggs in humans with moderate hypercholesterolemia. Pakistan Journal of Nutrition. 2014;12(10):907-911. | | | | Country, Study Duration
463 | Inamori T, Goda T, Kasezawa N, Yamakawa-Kobayashi K. The combined effects of genetic variation in the SIRT1 gene and dietary intake of n-3 and n-6 polyunsaturated fatty acids on serum LDL-C and HDL-C levels: a population based study. Lipids Health Dis. 2013;124. doi:10.1186/1476-511x-12-4 | X
464 | Intorre F, Venneria E, Finotti E, et al. Fatty acid content of serum lipid fractions and blood lipids in normolipidaemic volunteers fed two types of cheese having different fat compositions: a pilot study. Int J Food Sci Nutr. 2013;64(2):185-93. doi:10.3109/09637486.2012.710893 | | | | Duplicate data
465 | Iraj B, Heidari-Beni M, Bakhtiary-Broujeni M, et al. The effect of walnut consumption on lipid profiles of the first-degree relatives of type two diabetes mellitus patients (T2DM) with prediabetes. Pakistan Journal of Medical Sciences. 2013;29(Suppl 1.):280-284. doi:10.12669/pjms.291(Suppl).3517 | X
466 | Jaacks LM, Sher S, Staercke C, et al. Pilot randomized controlled trial of a Mediterranean diet or diet supplemented with fish oil, walnuts, and grape juice in overweight or obese US adults. BMC Nutr. 2018;4:26. doi:10.1186/s40795-018-0234-y | | X
467 | Jaaskelainen P, Magnussen CG, Pahkala K, et al. Childhood nutrition in predicting metabolic syndrome in adults: the cardiovascular risk in Young Finns Study. Diabetes Care. 2012;35(9):1937-43. doi:10.2337/dc12-0019 | | X | X
468 | Jacques H, Laurin D, Moorjani S, et al. Influence of diets containing cow’s milk or soy protein beverage on plasma lipids in children with familial hypercholesterolemia. J Am Coll Nutr. 1992. 11(Suppl):69s-73s. doi:10.1080/07315724.1992.10737988 | | X | | Health Status
469 | Jakicic JM, King WC, Marcus MD, et al. Short-term weight loss with diet and physical activity in young adults: The IDEA study. Obesity. 2015;23(12):2385-97. doi:10.1002/oby.21241 | | X
470 | Jakobsen MU, Gorst-Rasmussen A, Eriksen HH, et al. Trans fatty acids in adipose tissue and risk of myocardial infarction: a case-cohort study. PLoS One. 2018;13(8):e0202363. doi:10.1371/journal.pone.0202363 | X | X
471 | Jamar G, Pisani LP, Medeiros A, et al. Effect of fat intake on the inflammatory process and cardiometabolic risk in obesity after interdisciplinary therapy. Horm Metab Res. 2016;48(2):106-11. doi:10.1055/s-0035-1548871 | | X
472 | Jang J, Shin MJ, Kim OY, Park K. Longitudinal association between egg consumption and the risk of cardiovascular disease: interaction with type 2 diabetes mellitus. Nutr Diabetes. 2018;8(1):20. doi:10.1038/s41387-018-0033-1 | | X
473 | Jankovic N, Geelen A, Streppel MT, et al. WHO guidelines for a healthy diet and mortality from cardiovascular disease in European and American elderly: the CHANCES project. Am J Clin Nutr. 2015;102(4):745-56. doi:10.3945/ajcn.114.095117 | | X
474 | Jans A, Van Hees AMJ, Gjelstad IMF, et al. Impact of dietary fat quantity and quality on skeletal muscle fatty acid metabolism in subjects with the metabolic syndrome. Metabolism. 2012;61(11):1554-1565. doi:10.1016/j.metabol.2012.04.003 | | X
475 | Jenkins DJ, Jones PJ, Lamarche B, et al. Effect of a dietary portfolio of cholesterol-lowering foods given at 2 levels of intensity of dietary advice on serum lipids in hyperlipidemia: a randomized controlled trial. Jama. 2011;306(8):831-9. doi:10.1001/jama.2011.1202 | | X
476 | Jiang Z, Sim JS. Consumption of n-3 polyunsaturated fatty acid-enriched eggs and changes in plasma lipids of human subjects. Nutrition. 1993. 9(6):513-8. | | | | Age of participants at intervention or exposure
477 | Jiao J, Liu G, Shin HJ, et al. Dietary fats and mortality among patients with type 2 diabetes: analysis in two population based cohort studies. BMJ. 2019;366:l4009. doi:10.1136/bmj.l4009 | | | | Health Status
478 | Jin Y, Kanaya AM, Kandula NR, Rodriguez LA, Talegawkar SA. Vegetarian diets are associated with selected cardiometabolic risk factors among middle-older aged South Asians in the United States. J Nutr. 2018;148(12):1954-1960. doi:10.1093/jn/nxy217 | X
479 | Joensen AM, Overvad K, Dethlefsen C, et al. Marine n-3 polyunsaturated fatty acids in adipose tissue and the risk of acute coronary syndrome. Circulation. 2011;124(11):1232-8. doi:10.1161/circulationaha.110.987057 | | X
480 | Johansson I, Esberg A, Nilsson LM, Jansson JH, Wennberg P, Winkvist A. Dairy Product Intake and Cardiometabolic Diseases in Northern Sweden: A 33-Year Prospective Cohort Study. Nutrients. 2019;11(2): pii: E284. doi:10.3390/nu11020284 | | X
481 | Johns DJ, Lindroos AK, Jebb SA, Sjostrom L, Carlsson LM, Ambrosini GL. Dietary patterns, cardiometabolic risk factors, and the incidence of cardiovascular disease in severe obesity. Obesity (Silver Spring). 2015;23(5):1063-70. doi:10.1002/oby.20920 | | X
482 | Johnsen SH, Jacobsen BK, Braekkan SK, Hansen JB, Mathiesen EB. Fish consumption, fish oil supplements and risk of atherosclerosis in the Tromso study. Nutr J. 2018;17(1):56. doi:10.1186/s12937-018-0364-8 | | X
483 | Johnson MB, Burns-Whitmore B, Spalding T, Sancho-Madriz MF. Eating an avocado a day does not change body composition or blood cholesterol in healthy students. FASEB journal. 2013;27(Suppl 1). | | | | Publication Status
484 | Jones JL, Fernandez ML, McIntosh MS, et al. A Mediterranean-style low-glycemic-load diet improves variables of metabolic syndrome in women, and addition of a phytochemical-rich medical food enhances benefits on lipoprotein metabolism. J Clin Lipidol. 2011;5(3):188-196. doi:10.1016/j.jacl.2011.03.002 | | X
485 | Jones PJ, MacKay DS, Senanayake VK, et al. High-oleic canola oil consumption enriches LDL particle cholesteryl oleate content and reduces LDL proteoglycan binding in humans. Atherosclerosis. 2015;238(2):231-8. doi:10.1016/j.atherosclerosis.2014.12.010 | | | | Duplicate data
486 | Juanola-Falgarona M, Salas-Salvado J, Ibarrola-Jurado N, et al. Effect of the glycemic index of the diet on weight loss, modulation of satiety, inflammation, and other metabolic risk factors: a randomized controlled trial. Am J Clin Nutr. 2014;100(1):27-35. doi:10.3945/ajcn.113.081216 | | X
487 | Julibert A, Bibiloni MDM, Bouzas C, et al. Total and Subtypes of Dietary Fat Intake and Its Association with Components of the Metabolic Syndrome in a Mediterranean Population at High Cardiovascular Risk. Nutrients. 2019;11(7): pii: E1493. doi:10.3390/nu11071493 | X
488 | Jung H, Chen CO, Blumberg JB, Kwak HK. The effect of almonds on vitamin E status and cardiovascular risk factors in Korean adults: a randomized clinical trial. Eur J Nutr. 2018;57(6):2069-2079. doi:10.1007/s00394-017-1480-5 | | X
489 | Juraschek SP, Miller ER 3d, Weaver CM, Appel LJ. Effects of Sodium Reduction and the DASH Diet in Relation to Baseline Blood Pressure. J Am Coll Cardiol. 2017;70(23):2841-2848. doi:10.1016/j.jacc.2017.10.011 | | X
490 | Kabagambe EK, Ordovas JM, Hopkins PN, Tsai MY, Arnett DK. The relation between erythrocyte trans fat and triglyceride, VLDL- and HDL-cholesterol concentrations depends on polyunsaturated fat. PLoS One. 2012;7(10):e47430. doi:10.1371/journal.pone.0047430 | | X
491 | Kaippert VC, Dos Santos Lopes MCO, De Carvalho PD, Rosado EL. Effects of unsaturated fatty acids on weight loss, body composition and obesity related biomarkers. Diabetol Metab Syndr. 2015;7(Suppl 1): A139. doi: 10.1186/1758-5996-7-S1-A139 | | | | Publication Status
492 | Kalantarian S, Rimm EB, Herrington DM, Mozaffarian D. Dietary macronutrientsgenetic variationand progression of coronary atherosclerosis among women. Am Heart J. 2014;167(4):627-635.e1. doi:10.1016/j.ahj.2014.01.001 | | | X | Health Status
493 | Karamali M, Samimi M, Bahmani F, Foroozanfard F, Esmaillzadeh A. The effects of DASH diet on lipid profiles and biomarkers of oxidative stress in overweight and obese women with polycystic ovary syndrome: a randomised clinical trial. Human Reproduction. 2014;29i315- i316. doi:10.1093/humrep/29.Supplement_1.1 | | | | Publication Status
494 | Karatzi K, Aissopou EK, Tsirimiagou C, Fatmeli E, Sfikakis PP, Protogerou AD. Association of consumption of dairy products and meat with retinal vessel calibers in subjects at increased cardiovascular risk. Nutr Metab Cardiovasc Dis. 2016;26(8):752-7. doi:10.1016/j.numecd.2016.03.006 | X | X
495 | Karatzi K, Stamatelopoulos K, Lykka M, et al. Sesame oil consumption exerts a beneficial effect on endothelial function in hypertensive men. Eur J Prev Cardiol. 2013;20(2):202-8. doi:10.1177/2047487312437625 | | | X | Health Status
496 | Katoku Y, Yamada M, Yonekubo A, Kuwata T, Kobayashi A, Sawa A. Effect of the cholesterol content of a formula on the lipid compositions of plasma lipoproteins and red blood cell membranes in early infancy. Am J Clin Nutr. 1996. 64(6):871-7. doi:10.1093/ajcn/64.6.871 | | X
497 | Katz DL, Gnanaraj J, Treu JA, Ma Y, Kavak Y, Njike VY. Effects of egg ingestion on endothelial function in adults with coronary artery disease: a randomized, controlled, crossover trial. Am Heart J. 2015;169(1):162-9. doi:10.1016/j.ahj.2014.10.001 | | | | Health Status
498 | Kelemen L, Anand S. Sexual maturation, BMI, dietary intervention and dietary cholesterol reduced LDL cholesterol in children. Evid Based Cardiovasc Med. 1998. 2(2):58-60. | X | | | Health Status
499 | Kell KP, Cardel MI, Bohan Brown MM, Fernandez JR. Added sugars in the diet are positively associated with diastolic blood pressure and triglycerides in children. Am J Clin Nutr. 2014;100(1):46-52. doi:10.3945/ajcn.113.076505 | X
500 | Kemppainen T, Rosendahl A, Nuutinen O, Ebeling T, Pietinen P, Uusitupa M. Validation of a short dietary questionnaire and a qualitative fat index for the assessment of fat intake. Eur J Clin Nutr. 1993. 47(11):765-75. | | | X
501 | Kent LM, Grant RS, Watts G, Morton DP, Rankin PM, Ward EJ. HDL subfraction changes with a low-fat, plant-based Complete Health Improvement Program (CHIP). Asia Pac J Clin Nutr. 2018;27(5):1002-1009. doi:10.6133/apjcn.052018.05 | X | X
502 | Kesse-Guyot E, Fezeu L, Galan P, Hercberg S, Czernichow S, Castetbon K. Adherence to French nutritional guidelines is associated with lower risk of metabolic syndrome. J Nutr. 2011;141(6):1134-1139. doi:10.3945/jn.110.136317 | | | X
503 | Key TJ, Appleby PN, Bradbury KE, et al. Consumption of meat, fish, dairy products, and eggs and risk of ischemic heart disease. Circulation. 2019;139(25):2835-2845. doi:10.1161/circulationaha.118.038813 | | X
504 | Keys A, Menott A, Karvonen MJ, et al. The diet and 15-year death rate in the seven countries study. Am J Epidemiol. 2017;185(11):1130-1142. doi:10.1093/aje/kwx101 | X
505 | Khan SA, Jackson RT. Polyunsaturated fatty acids, inflammationand metabolic syndrome in South Asian Americans in Maryland. Food Sci Nutr. 2018;6(6):1575-1581. doi:10.1002/fsn3.698 | X
506 | Khare MM, Carpenter RA, Huber R, et al. Lifestyle intervention and cardiovascular risk reduction in the Illinois WISEWOMAN Program. J Womens Health. 2012. 21(3):294-301. doi:10.1089/jwh.2011.2926 | | X
507 | Kheirouri S, Mohajeri M, Haghighian HK. Nitric oxide, omega-3 fatty acids and blood pressure in prinzmetal angina. Curr Top Nutraceutical Res. 2015;13(2):89-93. | X
508 | Kiage JN, Merrill PD, Robinson CJ, et al. Intake of trans fat and all-cause mortality in the Reasons for Geographical and Racial Differences in Stroke (REGARDS) cohort. Am J Clin Nutr. 2013;97(5):1121-8. doi:10.3945/ajcn.112.049064 | | X
509 | Kiefte-de Jong JC, Chowdhury R, Franco OH. Fish intake or omega-3 fatty acids: greater than the sum of all parts?. Eur J Epidemiol. 2012;27(12):891-4. doi:10.1007/s10654-012-9757-8 | X
510 | Kien CL, Bunn JY, Stevens R, et al. Dietary intake of palmitate and oleate has broad impact on systemic and tissue lipid profiles in humans. Am J Clin Nutr. 2014;99(3):436-45. doi:10.3945/ajcn.113.070557 | | | | Study Duration
511 | Kim DS, Burt AA, Ranchalis JE, et al. Effects of dietary components on high-density lipoprotein measures in a cohort of 1,566 participants. Nutr Metab. 2014;11(1):44. doi:10.1186/1743-7075-11-44 | X | X
512 | Kim JE, Campbell WW. Dietary cholesterol contained in whole eggs is not well absorbed and does not acutely affect plasma total cholesterol concentration in men and women: results from 2 randomized controlled crossover studies. Nutrients. 2018;10(9): pii: E1272. doi:10.3390/nu10091272 | | X
513 | Kim KY, Park JS. Impact of fish consumption by subjects with prediabetes on the metabolic risk factors: using data in the 2015 (6th) Korea National Health and Nutrition Examination Surveys. Nutr Res Pract. 2018;12(3):233-242. doi:10.4162/nrp.2018.12.3.233 | X
514 | Kim M, Chae JS, Kim M, Lee SH, Lee JH. Effects of a 3-year dietary intervention on age-related changes in triglyceride and apolipoprotein A-V levels in patients with impaired fasting glucose or new-onset type 2 diabetes as a function of the APOA5 −1131 T > C polymorphism. Nutr J. 2014;13:40. doi:10.1186/1475-2891-13-40 | X | X
515 | Kim M, Kim M, Lee A, et al. Impact of 8-week linoleic acid intake in soy oil on Lp-PLA2 activity in healthy adults. Nutr Metab. 2017;14:32. doi:10.1186/s12986-017-0186-2 | | X
516 | Kim MS, Hwang SS, Park EJ, Bae JW. Strict vegetarian diet improves the risk factors associated with metabolic diseases by modulating gut microbiota and reducing intestinal inflammation. Environ Microbiol Rep. 2013;5(5):765-75. doi:10.1111/1758-2229.12079 | | X | X
517 | Kim OY, Chung HK, Shin MJ. Higher levels of serum triglyceride and dietary carbohydrate intake are associated with smaller LDL particle size in healthy Korean women. Nutr Res Pract. 2012;6(2):120-5. doi:10.4162/nrp.2012.6.2.120 | X | X
518 | Kim S, Kim J, Lim Y, Kim YJ, Kim JY, Kwon O. A dietary cholesterol challenge study to assess Chlorella supplementation in maintaining healthy lipid levels in adults: a double-blindedrandomizedplacebo-controlled study. Nutr J. 2016;15(1):54. doi:10.1186/s12937-016-0174-9 | | X
519 | Kim SA, Lee JK, Kang D, Shin S. Oily fish consumption and the risk of dyslipidemia in Korean adults: a prospective cohort study based on the Health Examinees Gem (HEXA-G) study. Nutrients. 2019;11(10): pii: E2506. doi:10.3390/nu11102506 | | X | X
520 | Kim YS, Xun P, Iribarren C, et al. Intake of fish and long-chain omega-3 polyunsaturated fatty acids and incidence of metabolic syndrome among American young adults: a 25-year follow-up study. Eur J Nutr. 2016;55(4):1707-16. doi:10.1007/s00394-015-0989-8 | | | X
521 | Kingah PL, Luu HN, Volcik KA, Morrison AC, Nettleton JA, Boerwinkle E. Association of NOS3 Glu298Asp SNP with hypertension and possible effect modification of dietary fat intake in the ARIC study. Hypertens Res. 2010;33(2):165-9. doi:10.1038/hr.2009.198 | X
522 | Kirkhus B, Lamglait A, Eilertsen KE, et al. Effects of similar intakes of marine n-3 fatty acids from enriched food products and fish oil on cardiovascular risk markers in healthy human subjects. Br J Nutr. 2012;107(9):1339-49. doi:10.1017/s0007114511004508 | | X
523 | Kishawy AT, Amer SA, Abd El-Hack ME, Saadeldin IM, Swelum AA. The impact of dietary linseed oil and pomegranate peel extract on broiler growth, carcass traits, serum lipid profile, and meat fatty acid, phenol, and flavonoid contents. Asian-Australas J Anim Sci. 2019;32(8):1161-1171. doi:10.5713/ajas.18.0522 | | X | | Non-human
524 | Kishimoto Y, Taguchi C, Saita E, et al. Additional consumption of one egg per day increases serum lutein plus zeaxanthin concentration and lowers oxidized low-density lipoprotein in moderately hypercholesterolemic males. Food Res Int. 2017;99(Pt 2):944-949. doi:10.1016/j.foodres.2017.03.003 | X | | | Health Status
525 | Kishimoto Y, Taguchi C, Suzuki-Sugihara N, et al. The effect of the consumption of egg on serum lipids and antioxidant status in healthy subjects. J Nutr Sci Vitaminol (Tokyo). 2016;62(5):361-365. doi:10.3177/jnsv.62.361 | X | X
526 | Knutsen SF, Knutsen R. The Tromso Survey: the Family Intervention study--the effect of intervention on some coronary risk factors and dietary habits, a 6-year follow-up. Prev Med. 1991. 20(2):197-212. doi:10.1016/0091-7435(91)90020-5 | | X
527 | Kodumuri N, Giamberardino L, Hinderliter A, Sen S. Association of dietary factors with progression of AA in stroke/TIA patients. J Neurol Disord. 2016;4(3): pii: 270. doi:10.4172/2329-6895.1000270 | | | | Health Status
528 | Kokanovic A, Mandic ML, Banjari I. Does individual dietary intervention have any impact on adolescents with cardiovascular health risks?. Med Glas (Zenica). 2014;11(1):234-7. | | X
529 | Kolarzyk E, Skop-Lewandowska A, Jaworska J, Ostachowska-Gasior A, Krzeszowska-Rosiek T. Dietary intake of antioxidants and fats in the context of coronary heart disease prevention among elderly people. Ann Agric Environ Med. 2018;25(1):131-136. doi:10.5604/12321966.1233574 | | | X
530 | Koletzko B. Trans fatty acids may impair biosynthesis of long-chain polyunsaturates and growth in man. Acta Paediatr. 1992. 81(4):302-6. doi:10.1111/j.1651-2227.1992.tb12230.x | | | | Health Status
531 | Kopecky SL, Klodas E, Alias S, Bauman J, Jew S, Jones PJ. LDL-C response to portfolio foods containing high levels of phytosterols, whole food fiber, and alpha-linoleic acid in statin reluctant patients: impact of CYP7A1-RS3808607 and apoe isoforms. Circulation. 2018;138:A17150 | | | | Publication Status
532 | Korrapati D, Jeyakumar SM, Putcha UK, et al. Coconut oil consumption improves fat-free mass, plasma HDL-cholesterol and insulin sensitivity in healthy men with normal BMI compared to peanut oil. Clin Nutr. 2018;38(6):2889-2899. doi:10.1016/j.clnu.2018.12.026 | | X | | Country
533 | Kovell LC, Yeung E, Miller ER, et al. The effect of healthy diets on subclinical cardiac injury and inflammation: results from the omni-heart trial. Circulation. 2018;138(Suppl 1). | | | | Publication Status
534 | Kralova Lesna I, Suchanek P, Brabcova E, Kovar J, Malinska H, Poledne R. Effect of different types of dietary fatty acids on subclinical inflammation in humans. Physiol Res. 2013;62(2):145-52. | | | | Health Status
535 | Kratz M, Weigle DS, Breen PA, et al. Exchanging carbohydrate or protein for fat improves lipid-related cardiovascular risk profile in overweight men and women when consumed ad libitum. J Investig Med. 2010;58(5):711-9. doi:10.231/JIM.0b013e3181da4d37 | | X
536 | Krishna S, Okhovat JP, Kim J, Kim CN. Influence of omega-3 fatty acids on triglyceride levels in patients using isotretinoin. JAMA Dermatol. 2015;151(1):101-2. doi:10.1001/jamadermatol.2014.2402 | | X | | Publication Status
537 | Kristensen M, Jensen MG, Aarestrup J, et al. Flaxseed dietary fibers lower cholesterol and increase fecal fat excretion, but magnitude of effect depend on food type. Nutr Metab. 2012;9(1):8-15. doi:10.1186/1743-7075-9-8 | | X
538 | Kromhout D, Menotti A, Alberti-Fidanza A, et al. Comparative ecologic relationships of saturated fat, sucrose, food groups, and a Mediterranean food pattern score to 50-year coronary heart disease mortality rates among 16 cohorts of the Seven Countries Study. Eur J Clin Nutr. 2018;72(8):1103-1110. doi:10.1038/s41430-018-0183-1 | X
539 | Ku CY, Gower BA, Nagy TR, Goran MI. Relationships between dietary fat, body fat, and serum lipid profile in prepubertal children. Obes Res. 1998. 6(6):400-7. | X
540 | Kuczmarski MF, Brewer BC, Rawal R, Pohlig RT, Zonderman AB, Evans MK. Aspects of dietary diversity differ in their association with atherosclerotic cardiovascular risk in a racially diverse us adult population. Nutrients. 2019;11(5). pii: E1034. doi:10.3390/nu11051034 | | X
541 | Kummer K, Jensen PN, Kratz M, et al. Full-fat dairy food intake is associated with a lower risk of incident diabetes among American Indians with low total dairy food intake. J Nutr. 2019;149(7):1238-1244. doi:10.1093/jn/nxz058 | | | X
542 | Kwiterovich PO, Barton BA, McMahon RP, et al. Effects of diet and sexual maturation on low-density lipoprotein cholesterol during puberty: the Dietary Intervention Study in Children (DISC). Circulation. 1997. 96(8):2526-33. doi:10.1161/01.cir.96.8.2526 | X | | | Health Status
543 | Kwiterovich PO. Safety and efficacy of treatment of children and adolescents with elevated low density lipoprotein levels with a step two diet or with lovastatin. Nutrition, metabolism, and cardiovascular diseases. Nutr Metab Cardiovasc Dis. 2001. 11(Suppl 5):30- 4. | X
544 | Laake I, Pedersen JI, Selmer R, et al. A prospective study of intake of trans-fatty acids from ruminant fat, partially hydrogenated vegetable oils, and marine oils and mortality from CVD. Br J Nutr. 2012;108(4):743-54. doi:10.1017/s0007114511005897 | | X
545 | Labbe SM, Noll C, Grenier-Larouche T, et al. Improved cardiac function and dietary fatty acid metabolism after modest weight loss in subjects with impaired glucose tolerance. Am J Physiol Endocrinol Metab. 2014;306(12):E1388-96. doi:10.1152/ajpendo.00638.2013 | | X | X
546 | Labonte ME, Jenkins DJ, Lewis GF, et al. Adding MUFA to a dietary portfolio of cholesterol-lowering foods reduces apoAI fractional catabolic rate in subjects with dyslipidaemia. Br J Nutr. 2013;110(3):426-36. doi:10.1017/s000711451200534x | | | | Health Status
547 | Labonte ME, Jenkins DJA, Lewis GF, et al. Impact of adding MUFA to a portfolio diet on in vivo kinetics of apo AI, B100 and B48 in subjects with hypercholesterolemia. FASEB journal. 2011;25(Suppl 1). | | | | Publication Status
548 | Labraimi H, Aguenaou H, Charrouf Z, et al. Impact of argane and olive oil consumption on metabolic syndrome indicators among menopausal women in Rabat, Morocco. Obesity Reviews. 2011;1289. doi:10.1111/j.1467-789X.2011.00889.x | | | | Publication Status
549 | Ladeia AM, Costa-Matos E, Barata-Passos R, Costa Guimaraes A. A palm oil-rich diet may reduce serum lipids in healthy young individuals. Nutrition. 2008. 24(1):11-5. doi:10.1016/j.nut.2007.08.013 | X
550 | Lagström H, Jokinen E, Seppänen R, et al. Fatty acids in serum lipid fractions as indicators of fat intake in 5- year-old children in the STRIP project. Scandinavian Journal of Nutrition. 1998. 42(4):140-144. | X | | X
551 | Lahoz C, Castillo E, Mostaza JM, et al. Relationship of the adherence to a Mediterranean diet and its main components with CRP levels in the Spanish population. Nutrients. 2018;10(3). pii: E379. doi:10.3390/nu10030379 | X | | X
552 | Lai HT, de Oliveira Otto MC, Lemaitre RN, et al. Serial circulating omega 3 polyunsaturated fatty acids and healthy ageing among older adults in the Cardiovascular Health Study: prospective cohort study. BMJ. 2018;363k4445. doi:10.1136/bmj.k4445 | | X
553 | Laitinen TT, Nuotio J, Juonala M, et al. Success in achieving the targets of the 20-Year infancy-onset dietary intervention: Association with insulin sensitivity and serum lipids. Diabetes Care. 2018;41(10):2236-2244. doi:10.2337/dc18-0869 | | X
554 | Lamarche B. Dietary sources of saturated fat may influence cardiovascular disease risk. Can Nurse. 2013;109(3):19. | X
555 | Lambert EA, Phillips S, Belski R, et al. Endothelial function in healthy young individuals is associated with dietary consumption of saturated fat. Front Physiol. 2017;8876. doi:10.3389/fphys.2017.00876 | X | | X
556 | Lambrinoudaki I, Augoulea A, Rizos D, et al. Greek-origin royal jelly improves the lipid profile of postmenopausal women. Gynecol Endocrinol. 2016;32(10):835-839. doi:10.1080/09513590.2016.1188281 | X | | X
557 | Lana A, Banegas JR, Guallar-Castillon P, Rodriguez-Artalejo F, Lopez-Garcia E. Association of dairy consumption and 24-Hour blood pressure in older adults with hypertension. Am J Med. 2018;131(10):1238-1249. doi:10.1016/j.amjmed.2018.04.039 | X | | | Health Status
558 | Lankinen M, Kolehmainen M, Jaaskelainen T, et al. Effects of whole grain, fish and bilberries on serum metabolic profile and lipid transfer protein activities: a randomized trial (Sysdimet). PLoS One. 2014;9(2):e90352. doi:10.1371/journal.pone.0090352 | | X | X
559 | Lapinleimu H, Jokinen E, Myyrinmaa A, et al. Individualized dietary counselling of families: serum cholesterol concentration and growth of children aged 7-13 months. Acta Paediatr. 1994. 83(4):383-8. doi:10.1111/j.1651-2227.1994.tb18124.x | | X
560 | Lapinleimu H, Vukari J, Nunikoski H, et al. Impact of gender, apolipoprotein E phenotypes, and diet on serum lipids and lipoproteins in infancy. J Pediatr. 1997. 131(6):825-32. doi:10.1016/s0022-3476(97)70028-3 | | X | | Duplicate data
561 | Larsson SC, Virtamo J, Wolk A. Dairy consumption and risk of stroke in Swedish women and men. Stroke. 2012;43(7):1775-80. doi:10.1161/strokeaha.111.641944 | | X
562 | Larsson SC, Virtamo J, Wolk A. Fish consumption and risk of stroke in Swedish women. Am J Clin Nutr. 2011;93(3):487-93. doi:10.3945/ajcn.110.002287 | | X
563 | Lassenius MI, Makinen VP, Fogarty CL, et al. Patients with type 1 diabetes show signs of vascular dysfunction in response to multiple high-fat meals. Nutr Metab. 2014;11(1):1-22. doi:10.1186/1743-7075-11-28 | X | X | | Health Status
564 | Lauer RM, Obarzanek E, Hunsberger SA, et al. Efficacy and safety of lowering dietary intake of total fat, saturated fat, and cholesterol in children with elevated LDL cholesterol: the Dietary Intervention Study in Children. Am J Clin Nutr. 2000. 72(Suppl 5):1332s-1342s. doi:10.1093/ajcn/72.5.1332s | | | | Duplicate data
565 | Laugesen M, Elliott R. Ischaemic heart diseaseType 1 diabetes, and cow milk A1 beta-casein. N Z Med J. 2003. 116(1168):U295. | X | X
566 | Laupsa Borge J, Veum VL, Eng Ø, et al. Very-high-fat and low-fat isocaloric diets exert similar metabolic benefits but different temporal effects on cardiometabolic risk markers. Obesity facts. 2016;9(Suppl 1):185- 186. doi:10.1159/000446744 | | | | Publication Status
567 | Lauritzen L, Harslof LB, Hellgren LI, Pedersen MH, Molgaard C, Michaelsen KF. Fish intake, erythrocyte n-3 fatty acid status and metabolic health in Danish adolescent girls and boys. Br J Nutr. 2012;107(5):697-704. doi:10.1017/s0007114511002418 | X
568 | Laursen ASD, Dahm CC, Johnsen SP, Schmidt EB, Overvad K, Jakobsen MU. Adipose tissue fatty acids present in dairy fat and risk of stroke: the Danish Diet, Cancer and Health cohort. Eur J Nutr. 2019;58(2):529-539. doi:10.1007/s00394-018-1608-2 | X | X
569 | Laursen ASD, Dahm CC, Johnsen SP, Tjonneland A, Overvad K, Jakobsen MU. Substitutions of dairy product intake and risk of stroke: a Danish cohort study. Eur J Epidemiol. 2018;33(2):201-212. doi:10.1007/s10654-017-0271-x | | X
570 | Laursen ASD, Sluijs I, Boer JMA, Verschuren WMM, van der Schouw YT, Jakobsen MU. Substitutions between dairy products and risk of stroke: results from the European Investigation into Cancer and Nutrition-Netherlands (EPIC-NL) cohort. Br J Nutr. 2019;121(12):1398-1404. doi:10.1017/s0007114519000564 | | X | X
571 | Lavigne JV, Gidding S, Stevens VJ, et al. A cholesterol-lowering diet does not produce adverse psychological effects in children: three-year results from the dietary intervention study in children. Health Psychol. 1999. 18(6):604-613. doi:10.1037/0278-6133.18.6.604 | | X | X
572 | Le T, Flatt SW, Natarajan L, et al. Effects of diet composition and insulin resistance status on plasma lipid levels in a weight loss intervention in women. J Am Heart Assoc. 2016;5(1). pii: e002771. doi:10.1161/jaha.115.002771 | | X
573 | Lee H, Jang HB, Yoo MG, Chung KS, Lee HJ. Protective effects of dietary MUFAs mediating metabolites against hypertension risk in the Korean Genome and Epidemiology Study. Nutrients. 2019;11(8).pii:E1928.doi:10.3390/nu11081928 | | | X
574 | Lee HA, Hwang HJ, Oh SY, et al. The differential effects of changes in individual macronutrient intake on changes in lipid concentrations during childhood: from the Ewha Birth & Growth Cohort. Clin Nutr. 2018;37(3):1027-1033. doi:10.1016/j.clnu.2017.04.017 | | X
575 | Lee J, Kim J. Association between dietary pattern and incidence of cholesterolemia in Korean adults: The Korean Genome and Epidemiology Study. Nutrients. 2018;10(1): pii: E53. doi:10.3390/nu10010053 | | X
576 | Lee JB, Notay K, Klingel SL, Chabowski A, Mutch DM, Millar PJ. Docosahexaenoic acid reduces resting blood pressure but increases muscle sympathetic outflow compared with eicosapentaenoic acid in healthy men and women. Am J Physiol Heart Circ Physiol. 2019. 316(4):H873- H881. doi:10.1152/ajpheart.00677.2018 | | X
577 | Lee SP, Dart AM, Walker KZ, O’Dea K, Chin-Dusting JP, Skilton MR. Effect of altering dietary n-6: n-3 PUFA ratio on cardiovascular risk measures in patients treated with statins: a pilot study. Br J Nutr. 2012;108(7):1280-5. doi:10.1017/s0007114511006519 | | | | Health Status
578 | Lee TC, Ivester P, Hester AG, et al. The impact of polyunsaturated fatty acid-based dietary supplements on disease biomarkers in a metabolic syndrome/diabetes population. Lipids Health Dis. 2014;13:196. doi:10.1186/1476-511x-13-196 | | X
579 | Lee YJ, Lee A, Yoo HJ, et al. Effect of weight loss on circulating fatty acid profiles in overweight subjects with high visceral fat area: a 12-week randomized controlled trial. Nutr J. 2018;17(1):28. doi:10.1186/s12937-018-0323-4 | | X
580 | Lee YJ, Seo JA, Yoon T, et al. Effects of low-fat milk consumption on metabolic and atherogenic biomarkers in Korean adults with the metabolic syndrome: a randomised controlled trial. J Hum Nutr Diet. 2016;29(4):477-86. doi:10.1111/jhn.12349 | | X
581 | Lee YJ, Song S, Song Y. High-carbohydrate diets and food patterns and their associations with metabolic disease in the Korean population. Yonsei Med J. 2018;59(7):834-842. doi:10.3349/ymj.2018.59.7.834 | X
582 | Lehtimaki T, Moilanen T, Porkka K, et al. Association between serum lipids and apolipoprotein E phenotype is influenced by diet in a population-based sample of free-living children and young adults: the Cardiovascular Risk in Young Finns Study. J Lipid Res. 1995. 36(4):653-61. | X
583 | Leichtle AB, Helmschrodt C, Ceglarek U, et al. Effects of a 2-y dietary weight-loss intervention on cholesterol metabolism in moderately obese men. Am J Clin Nutr. 2011;94(5):1189-1195. | | X
584 | Leite MLC, Prinelli F. A compositional data perspective on studying the associations between macronutrient balances and diseases. Eur J Clin Nutr. 2017;71(12):1365-1369. doi:10.1038/ejcn.2017.126 | X | X
585 | Lemos BS, Medina-Vera I, Blesso CN, Fernandez ML. Intake of 3 eggs per day when compared to a choline bitartrate supplement, downregulates cholesterol synthesis without changing the LDL/HDL ratio. Nutrients. 2018;10(2). pii: E258. doi:10.3390/nu10020258 | | X
586 | Lentjes MAH, Keogh RH, Welch AA, et al. Longitudinal associations between marine omega-3 supplement users and coronary heart disease in a UK population-based cohort. BMJ Open. 2017;7(10):e017471. doi:10.1136/bmjopen-2017-017471 | | X
587 | Letois F, Mura T, Scali J, Gutierrez LA, Féart C, Berr C. Nutrition and mortality in the elderly over 10 years of follow-up: The Three-City study. Br J Nutr. 2016;116(5):882-889. doi:10.1017/S000711451600266X | | X | X
588 | Li D, Wan Y, Wang F, et al. Effects of macronutrient distribution on weight change and related cardiometabolic profiles in healthy non-obese Chinese: a randomized, clinical trial. Ann Nutr Metab. 2017;71:689. doi:10.1159/000480486 | | | | Publication Status
589 | Lindstrom T, Kechagias S, Carlsson M, Nystrom FH. Transient increase in HDL-cholesterol during weight gain by hyperalimentation in healthy subjects. Obesity (Silver Spring). 2011;19(4):812-7. doi:10.1038/oby.2010.190 | | X
590 | Lipscomb ER, Caffrey HM, Hays LM, Finch EA, Saha CK, Ackermann RT. Lifestyle and Behavior. Lower fat intake is associated with lower weight and cholesterol at 4 months in adults with impaired glucose metabolism. Diabetes Spectrum. 2012;25(1):49-55. | | X
591 | Liu J, Joshi D, Sempos CT. Non-high-density-lipoprotein cholesterol and cardiovascular risk factors among adolescents with and without impaired fasting glucose. Applied PhysiologyNutrition & Metabolism. 2009. 34(2):136-142. doi:10.1139/H08-149 | X | X
592 | Liu JC, Conklin SM, Manuck SB, Yao JK, Muldoon MF. Long-chain omega-3 fatty acids and blood pressure. Am J Hypertens. 2011;24(10):1121-6. doi:10.1038/ajh.2011.120 | X
593 | Liu MJ, Li HT, Yu LX, et al. A correlation study of DHA dietary intake and plasma, erythrocyte and breast milk DHA concentrations in lactating women from Coastland, Lakeland, and Inland areas of China. Nutrients. 2016;8(5). pii: E312 doi:10.3390/nu8050312 | X | | X
594 | Liu PJ, Liu YP, Qin HK, Xing T, Li SS, Bao YY. Effects of polymorphism in FABP2 Ala54Thr on serum lipids and glycemic control in low glycemic index diets are associated with gender among Han Chinese with type 2 diabetes mellitus. Diabetes Metab Syndr Obes. 2019;12:413-421. doi:10.2147/dmso.S196738 | | | | Health Status
595 | Liu Q, Lichtenstein AH, Matthan NR, et al. Higher lipophilic index indicates higher risk of coronary heart disease in postmenopausal women. Lipids. 2017;52(8):687-702. doi:10.1007/s11745-017-4276-8 | | X
596 | Liu X, Kris-Etherton PM, West SG, et al. Effects of canola and high-oleic-acid canola oils on abdominal fat mass in individuals with central obesity. Obesity (Silver Spring). 2016;24(11):2261-2268. doi:10.1002/oby.21584 | | | X
597 | Liu Y, Poon S, Seeman E, Hare DL, Bui M, Iuliano S. Fat from dairy foods and ‘meat’ consumed within recommended levels is associated with favourable serum cholesterol levels in institutionalised older adults. J Nutr Sci. 2019;8: e10. doi:10.1017/jns.2019.5 | X
598 | Liu Y, Wang J, Zhang R, et al. A good response to oil with medium- and long-chain fatty acids in body fat and blood lipid profiles of male hypertriglyceridemic subjects. Asia Pac J Clin Nutr. 2009. 18(3):351-8. | | X
599 | Livingstone KM, Givens DI, Cockcroft JR, Pickering JE, Lovegrove JA. Is fatty acid intake a predictor of arterial stiffness and blood pressure in men? Evidence from the Caerphilly Prospective Study. Nutr Metab Cardiovasc Dis. 2013;23(11):1079-85. doi:10.1016/j.numecd.2012.12.002 | | | X
600 | Loganathan R, Vethakkan SR, Radhakrishnan AK, Razak GA, Kim-Tiu T. Red palm olein supplementation on cytokinese, ndothelial function and lipid profile in centrally overweight individuals: a randomised controlled trial. Eur J Clin Nutr. 2019;73(4):609-616. doi:10.1038/s41430-018-0236-5 | | X
601 | Loo RL, Zou X, Appel LJ, Nicholson JK, Holmes E. Characterization of metabolic responses to healthy diets and association with blood pressure: application to the Optimal Macronutrient Intake Trial for Heart Health (OmniHeart), a randomized controlled study. Am J Clin Nutr. 2018;107(3):323-334. doi:10.1093/ajcn/nqx072 | | | | Duplicate data
602 | Lopes MP, Giudici KV, Marchioni DM, Fisberg RM, Martini LA. Relationships between n-3 polyunsaturated fatty acid intake, serum 25 hydroxyvitamin D, food consumption, and nutritional status among adolescents. Nutr Res. 2015;35(8):681-8. doi:10.1016/j.nutres.2015.05.018 | X
603 | Lopez-Moreno J, Garcia-Carpintero S, Gomez-Delgado F, et al. Endotoxemia is modulated by quantity and quality of dietary fat in older adults. Exp Gerontol. 2018;109:119-125. doi:10.1016/j.exger.2017.11.006 | | | X
604 | Lorenzen J, Astrup A. The effect of dairy fat and calcium intake on fat digestibility and blood lipid profile. Obesity reviews. 2011;1290. doi:10.1111/j.1467-789X.2011.00889.x | | | | Publication Status
605 | Lorenzen JK, Astrup A. Dairy calcium intake modifies responsiveness of fat metabolism and blood lipids to a high-fat diet. Br J Nutr. 2011;105(12):1823-31. doi:10.1017/s0007114510005581 | | X
606 | Loring PA, Duffy LK, Murray MS. A risk-benefit analysis of wild fish consumption for various species in Alaska reveals shortcomings in data and monitoring needs. Sci Total Environ. 2010;408(20):4532-4541. doi:10.1016/j.scitotenv.2010.07.013 | X | X
607 | Loued S, Berrougui H, Componova P, Ikhlef S, Helal O, Khalil A. Extra-virgin olive oil consumption reduces the age-related decrease in HDL and Paraoxonase 1 anti-inflammatory activities. Br J Nutr. 2013;110(7):1272-1284. doi:10.1017/S0007114513000482 | X
608 | Louie JC, Flood VM, Burlutsky G, Rangan AM, Gill TP, Mitchell P. Dairy consumption and the risk of 15-year cardiovascular disease mortality in a cohort of older Australians. Nutrients. 2013;5(2):441-54. doi:10.3390/nu5020441 | | X
609 | Louie JC, Flood VM, Rangan AM, et al. Higher regular fat dairy consumption is associated with lower incidence of metabolic syndrome but not type 2 diabetes. Nutr Metab Cardiovasc Dis. 2013;23(9):816-21. doi:10.1016/j.numecd.2012.08.004 | | | X
610 | Lu Y, Feskens EJ, Dolle ME, et al. Dietary n-3 and n-6 polyunsaturated fatty acid intake interacts with FADS1 genetic variation to affect total and HDL-cholesterol concentrations in the Doetinchem Cohort Study. Am J Clin Nutr. 2010;92(1):258-65. doi:10.3945/ajcn.2009.29130 | X
611 | Luepker RV, Perry CL, McKinlay SM, et al. Outcomes of a field trial to improve children’s dietary patterns and physical activity. The Child and Adolescent Trial for Cardiovascular Health. CATCH collaborative group. JAMA. 1996. 275(10):768-76. doi:10.1001/jama.1996.03530340032026 | | X
612 | Lund ASQ, Hasselbalch AL, Gamborg M, et al. N-3 polyunsaturated fatty acids, body fat and inflammation. Obesity Facts. 2013;6(4):369-379. doi:10.1159/000354663 | X
613 | Lund EK, Lee-Finglas WE, Southon S, et al. Dietary fat intake and plasma lipid levels in adolescents. Eur J Clin Nutr. 1992. 46(12):857-64. | X
614 | Lutjohann D, Meyer S, von Bergmann K, Stellaard F. Cholesterol absorption and synthesis in vegetarians and omnivores. Mol Nutr Food Res. 2018;62(6):e1700689. doi:10.1002/mnfr.201700689 | X | | X
615 | Luukkonen PK, Sadevirta S, Umpleby M, et al. Effect of overfeeding diets enriched with unsaturated or saturated fatty acids or sugars on de novo lipogenesislipolysis and liver fat in humans. Diabetologia. 2016;59(1):S10- S11. doi:10.1007/s00125-016-4046-9 | | | | Publication Status
616 | Luukkonen PK, Sadevirta S, Zhou Y, et al. Saturated fat is more metabolically harmful for the human liver than unsaturated fat or simple sugars. Diabetes Care. 2018;41(8):1732-1739. doi:10.2337/dc18-0071 | | | | Study Duration
617 | Ma W, Wu JH, Wang Q, et al. Prospective association of fatty acids in the de novo lipogenesis pathway with risk of type 2 diabetes: the Cardiovascular Health Study. Am J Clin Nutr. 2015;101(1):153-63. doi:10.3945/ajcn.114.092601 | | | X
618 | Machado AM, de Paula H, Cardoso LD, Costa NM. Effects of brown and golden flaxseed on the lipid profile, glycemia, inflammatory biomarkers, blood pressure and body composition in overweight adolescents. Nutrition. 2015;31(1):90-6. doi:10.1016/j.nut.2014.05.002 | | X
619 | Machin DR, Park W, Alkatan M, Mouton M, Tanaka H. Effects of non-fat dairy products added to the routine diet on vascular function: a randomized controlled crossover trial. Nutr Metab Cardiovasc Dis. 2015;25(4):364-9. doi:10.1016/j.numecd.2015.01.005 | | X
620 | Machin DR, Park W, Alkatan M, Mouton M, Tanaka H. Hypotensive effects of solitary addition of conventional nonfat dairy products to the routine diet: a randomized controlled trial. Am J Clin Nutr. 2014;100(1):80-7. doi:10.3945/ajcn.114.085761 | | X
621 | MacKay DS, Cardillo A, Mollard RC, Jones PJ. Hemp food product consumption for 4 weeks raises red blood cell alpha linolenic acid, but not total n-3 polyunsaturated fatty acid content, compared to a soybean and sesame control product in free living participants who are overweight or obese. FASEB journal. 2017;31(1) | | | | Publication Status
622 | Macknin M, Kong T, Weier A, et al. Plant-based, no-added-fat or American Heart Association diets: impact on cardiovascular risk in obese children with hypercholesterolemia and their parents. J Pediatr. 2015;166(4):953-9.e1-3. doi:10.1016/j.jpeds.2014.12.058 | | X
623 | Madjd A, Taylor MA, Mousavi N, et al. Comparison of the effect of daily consumption of probiotic compared with low-fat conventional yogurt on weight loss in healthy obese women following an energy-restricted diet: a randomized controlled trial. Am J Clin Nutr. 2016;103(2):323-9. doi:10.3945/ajcn.115.120170 | | X
624 | Madsen MTB, Bjerregaard AA, Furtado JD, et al. Comparisons of estimated intakes and plasma concentrations of selected fatty acids in pregnancy. Nutrients. 2019;11(3): pii: E568. doi:10.3390/nu11030568 | X | | X
625 | Magriplis E, Mitsopoulou AV, Karageorgou D, et al. Frequency and quantity of egg intake is not associated with dyslipidemia: the Hellenic National Nutrition and Health Survey (HNNHS). Nutrients. 2019;11(5): pii: E1105. doi:10.3390/nu11051105 | X | X
626 | Mah E, Sapper TN, Chitchumroonchokchai C, et al. alpha-Tocopherol bioavailability is lower in adults with metabolic syndrome regardless of dairy fat co-ingestion: a randomized, double-blind, crossover trial. Am J Clin Nutr. 2015;102(5):1070-80. doi:10.3945/ajcn.115.118570 | | | X
627 | Mah E, Schulz JA, Kaden VN, et al. Cashew consumption reduces total and ldl cholesterol in mildly hypercholesterolemic men and women: a randomized, crossover, controlled feeding trial. FASEB journal. 2017;31(Suppl 1) | | | | Publication Status
628 | Mah E, Schulz JA, Kaden VN, et al. Cashew consumption reduces total and LDL cholesterol: a randomized, crossover, controlled-feeding trial. Am J Clin Nutr. 2017;105(5):1070-1078. doi:10.3945/ajcn.116.150037 | | | | Health Status
629 | Mahe G, Ronziere T, Laviolle B, et al. An unfavorable dietary pattern is associated with symptomatic ischemic stroke and carotid atherosclerosis. J Vasc Surg. 2010;52(1):62-8. doi:10.1016/j.jvs.2010.02.258 | X
630 | Maki KC, Hasse W, Dicklin MR, et al. Corn oil lowers plasma cholesterol compared with coconut oil in adults with above-desirable levels of cholesterol in a randomized crossover trial. J Nutr. 2018;148(10):1556-1563. doi:10.1093/jn/nxy156 | | | | Health Status
631 | Maki KC, Lawless AL, Kelley KM, Kaden VN, Geiger CJ, Dicklin MR. Corn oil improves the plasma lipoprotein lipid profile compared with extra-virgin olive oil consumption in men and women with elevated cholesterol: results from a randomized controlled feeding trial. J Clin Lipidol. 2015;9(1):49-57. doi:10.1016/j.jacl.2014.10.006 | | | | Health Status
632 | Maki KC, Lawless AL, Kelley KM, et al. Corn oil intake favorably impacts lipoprotein cholesterolapolipoprotein and lipoprotein particle levels compared with extra-virgin olive oil. Eur J Clin Nutr. 2017;71(1):33-38. doi:10.1038/ejcn.2016.169 | | | X | Study Duration
633 | Maki KC, Palacios OM, Lindner E, Nieman KM, Bell M, Sorce J. Replacement of refined starches and added sugars with egg protein and unsaturated fats increases insulin sensitivity and lowers triglycerides in overweight or obese adults with elevated triglycerides. J Nutr. 2017;147(7):1267-1274. doi:10.3945/jn.117.248641 | | X | | Health Status
634 | Maki KC, Rains TM, Schild AL, et al. Effects of low-fat dairy intake on blood pressureendothelial function, and lipoprotein lipids in subjects with prehypertension or stage 1 hypertension. Vasc Health Risk Manag. 2013;9369-79. doi:10.2147/vhrm.S45684 | | X
635 | Malpuech-Brugere C, Mouriot J, Boue-Vaysse C, et al. Differential impact of milk fatty acid profiles on cardiovascular risk biomarkers in healthy men and women. Eur J Clin Nutr. 2010;64(7):752-9. doi:10.1038/ejcn.2010.73 | | X | | Study Duration
636 | Malve H, Kerkar P, Mishra N, et al. LDL-cholesterol lowering activity of a blend of rice bran oil and safflower oil (8:2) in patients with hyperlipidaemia: a proof of concept, double blind, controlled, randomised parallel group study. J Indian Med Assoc. 2010;108(11):785-8. | | | | Country
637 | Manios Y, Moschandreas J, Hatzis C, Kafatos A. Health and nutrition education in primary schools of Crete: changes in chronic disease risk factors following a 6-year intervention programme. Br J Nutr. 2002;88(3):315-24. doi:10.1079/bjn2002672 | | X
638 | Mann JI, Appleby PN, Key TJ, Thorogood M. Dietary determinants of ischaemic heart disease in health conscious individuals. Heart. 1997. 78(5):450-5. doi:10.1136/hrt.78.5.450 | | | | Age of participants at intervention or exposure
639 | Manninen S, Lankinen M, Erkkila A, et al. The effect of intakes of fish and Camelina sativa oil on atherogenic and anti-atherogenic functions of LDL and HDL particles: a randomized controlled trial. Atherosclerosis. 2019;281:56-61. doi:10.1016/j.atherosclerosis.2018.12.017 | | | X
640 | Manninen SM, Lankinen MA, de Mello VD, Laaksonen DE, Schwab US, Erkkila AT. Intake of fatty fish alters the size and the concentration of lipid components of HDL particles and camelina sativa oil decreases IDL particle concentration in subjects with impaired glucose metabolism. Mol Nutr Food Res. 2018;62(10):e1701042. doi:10.1002/mnfr.201701042 | | | | Product not widely available in US
641 | Mansoorian B, Chen Y, Mullen W, Combet E. Impact of dietary fat replacement with rapeseed or sunflower oils on biomarkers of cardiovascular disease in healthy adults with overweight / obesity. Obesity facts. 2019;12205- . doi:10.1159/000489691 | | | | Publication Status
642 | Mansour M, Nassef YE, Shady MA, Aziz AA, Malt HA. Metabolic syndrome and cardiovascular risk factors in obese adolescent. Open Access Maced J Med Sci. 2016;4(1):118-21. doi:10.3889/oamjms.2016.037 | X | | | Country
643 | Maranhao PA, Kraemer-Aguiar LG, de Oliveira CL, et al. Brazil nuts intake improves lipid profile, oxidative stress and microvascular function in obese adolescents: a randomized controlled trial. Nutr Metab (Lond). 2011;8(1):32. doi:10.1186/1743-7075-8-32 | | X
644 | Marchioni DM, de Oliveira MF, Carioca AAF, et al. Plasma fatty acids: Biomarkers of dietary intake?. Nutrition. 2019;59:77-82. doi:10.1016/j.nut.2018.08.008 | X | | X
645 | Markey O, Vasilopoulou D, Jackson KG, Todd S, Givens DI, Lovegrove JA. Postprandial lipid responses after long-term intake of dairy products varying in fatty acid composition. Ann Nutr Metab. 2017;71346- . doi:10.1159/000480486 | | | | Publication Status
646 | Markey O, Vasilopoulou D, Kliem KE, et al. Plasma phospholipid fatty acid profile confirms compliance to a novel saturated fat-reduced, monounsaturated fat-enriched dairy product intervention in adults at moderate cardiovascular risk: a randomized controlled trial. Nutr J. 2017;16(1):33. doi:10.1186/s12937-017-0249-2 | | | X
647 | Markhus MW, Rasinger JD, Malde MK, et al. Docosahexaenoic acid status in pregnancy determines the maternal docosahexaenoic acid status 3-, 6- and 12 months postpartum. Results from a longitudinal observational study. PLoS One. 2015;10(9):e0136409. doi:10.1371/journal.pone.0136409 | | X | X
648 | Markun S. Cardiovascular primary prevention with omega 3 fatty acids: no effect on mortality. Praxis. 2013;102(17):1076- 1077. doi:10.1024/1661-8157/a001392 | | | | Language
649 | Martinez-Gonzalez MA, Sanchez-Tainta A, Corella D, et al. A provegetarian food pattern and reduction in total mortality in the Prevencion con Dieta Mediterranea (PREDIMED) study. Am J Clin Nutr. 2014;100(Suppl 1):320s-8s. doi:10.3945/ajcn.113.071431 | | X
650 | Martinez-Gonzalez MA, Toledo E, Aros F, et al. Extravirgin olive oil consumption reduces risk of atrial fibrillation: the PREDIMED (Prevencion con Dieta Mediterranea) trial. Circulation. 2014;130(1):18-26. doi:10.1161/circulationaha.113.006921 | | X | X
651 | Martinez-Gonzalez MA, Zazpe I, Razquin C, et al. Empirically-derived food patterns and the risk of total mortality and cardiovascular events in the PREDIMED study. Clin Nutr. 2015;34(5):859-67. doi:10.1016/j.clnu.2014.09.006 | | X
652 | Martino F, Martino E, Versacci P, Niglio T, Zanoni C, Puddu PE. Lifestyle and awareness of cholesterol blood levels among 29159 community school children in Italy. Nutr Metab Cardiovasc Dis. 2019;29(8):802-807. doi:10.1016/j.numecd.2019.05.060 | X | X
653 | Maruyama C, Nakano R, Shima M, et al. Effects of a Japan diet intake program on metabolic parameters in middle-aged men. J Atheroscler Thromb. 2017;24(4):393-401. doi:10.5551/jat.36780 | X | | X
654 | Marzuki A, Arshad F, Razak TA, Jaarin K. Influence of dietary fat on plasma lipid profiles of Malaysian adolescents. Am J Clin Nutr. 1991. 53(Suppl 4):1010s-1014s. doi:10.1093/ajcn/53.4.1010S | | | | Country
655 | Maslova E, Rifas-Shiman SL, Olsen SF, Gillman MW, Oken E. Prenatal n-3 long-chain fatty acid status and offspring metabolic health in early and mid-childhood: results from Project Viva. Nutr Diabetes. 2018;8(1):29. doi:10.1038/s41387-018-0040-2 | | | | Population at Outcome
656 | Mason AE, Saslow LR, Moran PJ, et al. Lipid findings from the Diabetes Education to Lower Insulin Sugars and Hunger (DELISH) Study. Nutr Metab (Lond). 2019;16:58. doi:10.1186/s12986-019-0383-2 | | | | Health Status
657 | Masquio DC, de Piano A, Campos RM, et al. Saturated fatty acid intake can influence increase in plasminogen activator inhibitor-1 in obese adolescents. Horm Metab Res. 2014;46(4):245-51. doi:10.1055/s-0034-1370908 | X
658 | Masquio DC, de Piano-Ganen A, Oyama LM, et al. The role of free fatty acids in the inflammatory and cardiometabolic profile in adolescents with metabolic syndrome engaged in interdisciplinary therapy. J Nutr Biochem. 2016;33:136-44. doi:10.1016/j.jnutbio.2016.03.017 | | X
659 | Mateo-Gallego R, Perez-Calahorra S, Bea AM, et al. Effects of lean red meat or lean white meat intake on the lipid profile in women: a randomized crossover study. Atheroscler Suppl. 2011;12(1):141. | | | | Publication Status
660 | Mateo-Gallego R, Perez-Calahorra S, Cenarro A, et al. Effect of lean red meat from lamb v. lean white meat from chicken on the serum lipid profile: a randomised cross-over study in women. Br J Nutr. 2012;107(10):1403-7. doi:10.1017/s0007114511004545 | | X
661 | Matsumoto C, Yoruk A, Wang L, Gaziano JM, Sesso HD. Fish and omega-3 fatty acid consumption and risk of hypertension. J Hypertens. 2019;37(6):1223-1229. doi:10.1097/hjh.0000000000002062 | | | X
662 | Mayneris-Perxachs J, Bondia-Pons I, Serra-Majem L, Castellote AI, López-Sabater MC. Long-chain n-3 fatty acids and classical cardiovascular disease risk factors among the Catalan population. Food Chem. 2010;119(1):54-61. doi:10.1016/j.foodchem.2009.05.073 | X
663 | Mayr H, Bendall C, Tierney A, Kingsley M, Radcliffe J, Itsiopoulos C, Thomas C. A multi-ethnic australian cohort with coronary heart disease adhere well to a Mediterranean diet intervention and improve plasma adiponectin levels. Ann Nutr Metab. 2017;71:906- 907. doi:10.1159/000480486 | | | | Publication Status
664 | Mayr HL, Tierney AC, Kucianski T, Thomas CJ, Itsiopoulos C. Australian patients with coronary heart disease achieve high adherence to 6-month Mediterranean diet intervention: preliminary results of the AUSMED Heart Trial. Nutrition. 2019;61:21-31. doi:10.1016/j.nut.2018.10.027 | | | X | Health Status
665 | Mazidi M, Pennathur S, Afshinnia F. Link of dietary patterns with metabolic syndrome: analysis of the National Health and Nutrition Examination Survey. Nutr Diabetes. 2017;7(3): e255. doi:10.1038/nutd.2017.11 | X
666 | Mazza E, Ferro Y, Lamprinoudi T, et al. Relationship between high sodium and low PUFA intake and carotid atherosclerosis in elderly women. Exp Gerontol. 2018;108256-261. doi:10.1016/j.exger.2018.05.004 | X
667 | McCaffery JM, Poque-Geile MF, Muldoon MF, Debski TT, Wing RR, Manuck SB. The nature of the association between diet and serum lipids in the community: a twin study. Health Psychol. 2001. 20(5):341-50. doi:10.1037//0278-6133.20.5.341 | X
668 | McEneny J, McPherson P, Spence M, et al. Does a diet high or low in fat influence the oxidation potential of VLDL, LDL and HDL subfractions?. Nutr Metab Cardiovasc Dis. 2013;23(7):612-8. doi:10.1016/j.numecd.2011.12.007 | | X
669 | McKay DL, Chen CY, Yeum KJ, Matthan NR, Lichtenstein AH, Blumberg JB. Chronic and acute effects of walnuts on antioxidant capacity and nutritional status in humans: a randomized, cross-over pilot study. Nutr J. 2010;9:21. doi:10.1186/1475-2891-9-21 | | X
670 | Medenwald D, Kluttig A, Lacruz ME, Schumann J. Serum dietary fatty acids and coronary heart disease risk - A nested case-control-study within the CARLA cohort. Nutr Metab Cardiovasc Dis. 2019;29(2):152-158. doi:10.1016/j.numecd.2018.10.006 | X | X
671 | Meier T, Grafe K, Senn F, et al. Cardiovascular mortality attributable to dietary risk factors in 51 countries in the WHO European Region from 1990 to 2016: a systematic analysis of the Global Burden of Disease Study. Eur J Epidemiol. 2019;34(1):37-55. doi:10.1007/s10654-018-0473-x | X | X
672 | Melanson KJ, Summers A, Nguyen V, et al. Body compositiondietary composition and components of metabolic syndrome in overweight and obese adults after a 12-week trial on dietary treatments focused on portion control, energy density, or glycemic index. Nutr J. 2012;11(57). doi:10.1186/1475-2891-11-57 | | X
673 | Mellendick K, Shanahan L, Wideman L, Calkins S, Keane S, Lovelady C. Diets rich in fruits and vegetables are associated with lower cardiovascular disease risk in adolescents. Nutrients. 2018;10(2):E136. doi:10.3390/nu10020136 | X | X
674 | Meng H, Matthan NR, Wu D, et al. Comparison of diets enriched in stearic, oleic, and palmitic acids on inflammation, immune response, cardiometabolic risk factors, and fecal bile acid concentrations in mildly hypercholesterolemic postmenopausal women-randomized crossover trial. Am J Clin Nutr. 2019;110(2):305-315. doi:10.1093/ajcn/nqz095 | | X | | Health Status
675 | Menotti A, Kromhout D, Puddu PE, et al. Baseline fatty acids food groups a diet score and 50-year all-cause mortality rates. An ecological analysis of the Seven Countries Study. Ann Med. 2017;49(8):718-727. doi:10.1080/07853890.2017.1372622 | | | X
676 | Mente A, Dehghan M, Rangarajan S, et al. Association of dietary nutrients with blood lipids and blood pressure in 18 countries: a cross-sectional analysis from the PURE study. Lancet Diabetes Endocrinol. 2017;5(10):774-787. doi:10.1016/s2213-8587(17)30283-8 | X
677 | Merino J, Sala-Vila A, Kones R, et al. Increasing long-chain n-3PUFA consumption improves small peripheral artery function in patients at intermediate-high cardiovascular risk. J Nutr Biochem. 2014;25(6):642-6. doi:10.1016/j.jnutbio.2014.02.004 | | | X
678 | Mertens E, Markey O, Geleijnse JM, Givens DI, Lovegrove JA. Dietary patterns in relation to cardiovascular disease incidence and risk markers in a middle-aged British male population: data from the Caerphilly Prospective Study. Nutrients. 2017;9(1): pii: E75. doi:10.3390/nu9010075 | | X
679 | Metkus TS, Dobrosielski D, Stewart K. Effect of a low carbohydrate versus a low fat diet on the metabolic syndrome. J Am Coll Cardiol. 2012;59(13 Suppl 1):e1753. doi: 10.1016/s0735-1097(12)61754-9 | | | | Publication Status
680 | Micha R, Penalvo JL, Cudhea F, Imamura F, Rehm CD, Mozaffarian D. Association between dietary factors and mortality from heart disease, stroke and type 2 diabetes in the United States. JAMA. 2017;317(9):912-924. doi:10.1001/jama.2017.0947 | X
681 | Mielgo-Ayuso J, Collado PS, Urdampilleta A, Martinez-Sanz JM, Seco J. Changes induced by diet and nutritional intake in the lipid profile of female professional volleyball players after 11 weeks of training. J Int Soc Sports Nutr. 2013;10(1):55. doi:10.1186/1550-2783-10-55 | | X
682 | Mietus-Snyder M, Baker AL, Neufeld EJ, et al. Effects of nutritional counseling on lipoprotein levels in a pediatric lipid clinic. Am J Dis Child. 1993. 147(4):378-81. doi:10.1001/archpedi.1993.02160280028012 | X | X
683 | Miglani N, Bains K, Singh P. Diet and physical activity in relation to metabolic syndrome among urban Indian men and women. Ecol Food Nutr. 2015;54(1):43-56. doi:10.1080/03670244.2014.947403 | X | | | Country
684 | Mikkila V, Rasanen L, Raitakari OT, et al. Major dietary patterns and cardiovascular risk factors from childhood to adulthood. The Cardiovascular Risk in Young Finns Study. Br J Nutr. 2007. 98(1):218-25. doi:10.1017/s0007114507691831 | | X
685 | Milajerdi A, Shakeri F, Keshteli AH, et al. Dietary total antioxidant capacity in relation to stroke among Iranian adults. Nutr Neurosci. 2019;1-6. doi:10.1080/1028415x.2018.1520478 | X | X
686 | Miller C, Karimi R, Silbernagel S, et al. Mercury, omega-3 fatty acids and seafood intake are not associated with heart rate variability or QT interval. Arch Environ Occup Health. 2018;73(4):251-257. doi:10.1080/19338244.2017.1315360 | X
687 | Miller ER, Cooper LA, Carson KA, et al. A dietary intervention in urban African Americans: results of the “Five Plus Nuts and Beans” randomized trial. Am J Prev Med. 2016;50(1):87- 95. doi:10.1016/j.amepre.2015.06.010 | | X
688 | Min C, Noh H, Kang YS, et al. Skipping breakfast is associated with diet quality and metabolic syndrome risk factors of adults. Nutr Res Pract. 2011;5(5):455-63. doi:10.4162/nrp.2011.5.5.455 | X | X
689 | Minoura A, Wang DH, Sato Y, et al. Association of dietary fat and carbohydrate consumption and predicted ten-year risk for developing coronary heart disease in a general Japanese population. Acta Med Okayama. 2014;68(3):129-35. doi:10.18926/amo/52652 | X
690 | Mirmiran P, Asghari G, Farhadnejad H, Eslamian G, Hosseini-Esfahani F, Azizi F. Low carbohydrate diet is associated with reduced risk of metabolic syndrome in Tehranian adults. Int J Food Sci Nutr. 2017;68(3):358-365. doi:10.1080/09637486.2016.1242119 | | X
691 | Mirmiran P, Yousefi R, Mottaghi A, Azizi F. Advanced glycation end products and risk of hypertension in Iranian adults: Tehran lipid and glucose study. J Res Med Sci. 2018;23:43. doi:10.4103/jrms.JRMS_982_17 | | X
692 | Mitra SR, Tan PY, Amini F. Association of ADRB2 rs1042713 with obesity and obesity-related phenotypes and its interaction with dietary fat in modulating Glycaemic Indices in Malaysian Adults. J Nutr Metab. 2019;2019:8718795. doi:10.1155/2019/8718795 | X
693 | Miura K, Stamler J, Brown IJ, et al. Relationship of dietary monounsaturated fatty acids to blood pressure: the International Study of Macro/Micronutrients and Blood Pressure. J Hypertens. 2013;31(6):1144- 1150. doi:10.1097/HJH.0b013e3283604016 | X
694 | Mize CE, Uauy R, Kramer R, Benser M, Allen S, Grundy SM. Lipoprotein-cholesterol responses in healthy infants fed defined diets from ages 1 to 12 months: comparison of diets predominant in oleic acid versus linoleic acidwith parallel observations in infants fed a human milk-based diet. J Lipid Res. 1995. 36(6):1178-87. | | X
695 | Mohammadifard N, Hosseini M, Sajjadi F, Maghroun M, Boshtam M, Nouri F. Comparison of effects of soft margarine, blended, ghee, and unhydrogenated oil with hydrogenated oil on serum lipids: A randomized clinical trail. ARYA Atheroscler. 2013;9(6):363-71. | | X
696 | Mohammadifard N, Nazem M, Naderi GA, et al. Effect of hydrogenated, liquid and ghee oils on serum lipids profile. ARYA Atheroscler. 2010;6(1):16-22. | | X
697 | Mohammadifard N, Talaei M, Sadeghi M, et al. Dietary patterns and mortality from cardiovascular disease: Isfahan Cohort Study. Eur J Clin Nutr. 2017;71(2):252- 258. doi:10.1038/ejcn.2016.170 | | X | | Country
698 | Molero-Conejo E, Morales LM, Fernandez V, et al. Lean adolescents with increased risk for metabolic syndrome. Arch Latinoam Nutr. 2003. 53(1):39-46. | | | | Country
699 | Monge R, Beita O. Prevalence of coronary heart disease risk factors in Costa Rican adolescents. J Adolesc Health. 2000. 27(3):210-7. doi:10.1016/s1054-139x(99)00017-8 | X
700 | Monge-Rojas R, Campos H, Fernandez Rojas X. Saturated and cis- and trans-unsaturated fatty acids intake in rural and urban Costa Rican adolescents. J Am Coll Nutr. 2005. 24(4):286-93. doi:10.1080/07315724.2005.10719476 | X
701 | Montserrat-de la Paz S, Lopez S, Bermudez B, Guerrero JM, Abia R, Muriana FJ. Effects of immediate-release niacin and dietary fatty acids on acute insulin and lipid status in individuals with metabolic syndrome. J Sci Food Agric. 2018;98(6):2194-2200. doi:10.1002/jsfa.8704 | | | X
702 | Moreno JP, Johnston CA, El-Mubasher AA, et al. Peanut consumption in adolescents is associated with improved weight status. Nutr Res. 2013;33(7):552-6. doi:10.1016/j.nutres.2013.05.005 | X | X
703 | Moreno-Luna R, Munoz-Hernandez R, Miranda ML, et al. Olive oil polyphenols decrease blood pressure and improve endothelial function in young women with mild hypertension. Am J Hypertens. 2012;25(12):1299-304. doi:10.1038/ajh.2012.128 | | X
704 | Morgantini C, Trifiro S, Trico D, et al. A short-term increase in dietary cholesterol and fat intake affects high-density lipoprotein composition in healthy subjects. Nutr Metab Cardiovasc Dis. 2018;28(6):575-581. doi:10.1016/j.numecd.2018.03.005 | | X
705 | Morrison MC, Mulder P, Stavro PM, et al. Replacement of dietary saturated fat by PUFA-rich pumpkin seed oil attenuates non-alcoholic fatty liver disease and atherosclerosis development, with additional health effects of virgin over refined oil. PLoS One. 2015;10(9):e0139196. doi:10.1371/journal.pone.0139196 | | | | Non-human
706 | Mossaheb N, Papageorgiou K, Schafer MR, Becker J, Schloegelhofer M, Amminger GP. Changes in triglyceride levels in ultra-high risk for psychosis individuals treated with omega-3 fatty acids. Early Interv Psychiatry. 2018;12(1):30-36. doi:10.1111/eip.12275 | | X
707 | Mousavi SM, Milajerdi A, Pouraram H, et al. Adherence to alternative Healthy Eating Index (AHEI-2010) is not associated with risk of stroke in Iranian adults: a case-control study. Int J Vitam Nutr Res. 2019;1-8. doi:10.1024/0300-9831/a000603 | X
708 | Mozaffarian D, Appel LJ, Van Horn L. Components of a cardioprotective diet: New insights. Circulation. 2011;123(24):2870-2891. doi:10.1161/circulationaha.110.968735 | X
709 | Mueller C, Masri B, Hogg J, Mastrogiacomo M, Chiu YL. Carbohydrate- vs fat-controlled diet effect on weight loss and coronary artery disease risk: a pilot feeding study. Nutr Clin Pract. 2010;25(5):542-7. doi:10.1177/0884533610379854 | | X
710 | Mueller NT. Effects of macronutrients on serum short chain fatty acids (SCFA): results from the optimal macro-nutrient intake to prevent heart disease (OmniHeart) trial. Circulation. 2019;139. doi:10.1161/circ.139.suppl_1.MP68 | | | | Publication Status
711 | Muka T, Blekkenhorst LC, Lewis JR, et al. Dietary fat compositiontotal body fat and regional body fat distribution in two Caucasian populations of middle-aged and older adult women. Clin Nutr. 2017;36(5):1411-1419. doi:10.1016/j.clnu.2016.09.018 | | | X
712 | Mytton OT, Forouhi NG, Scarborough P, et al. Association between intake of less-healthy foods defined by the United Kingdom’s nutrient profile model and cardiovascular disease: a population-based cohort study. PLoS Med. 2018;15(1):e1002484. doi:10.1371/journal.pmed.1002484 | | X
713 | Nagashree RS, Manjunath NK, Indu M, et al. Effect of a diet enriched with fresh coconut saturated fats on plasma lipids and erythrocyte fatty acid composition in normal adults. J Am Coll Nutr. 2017;36(5):330-334. doi:10.1080/07315724.2017.1280713 | | | | Country
714 | Nakabou M, Kai T, Maeshima T, Kanamasa K. Relationship between EPA or EPA/AA and arteriosclerosis in elderly patients over 80 years old. Japanese Journal of Geriatrics. 2011;48(6):672-678. doi:10.3143/geriatrics.48.672 | | | | Language
715 | Nakamura Y, Okuda N, Turin TC, et al. Fatty acids intakes and serum lipid profiles: NIPPON DATA90 and the national nutrition monitoring. J Epidemiol. 2010;20(Suppl 3):S544-8. doi:10.2188/jea.je20090223 | X
716 | Nakamura Y, Ueshima H, Okuda N, et al. Relationship of three different types of low-carbohydrate diet to cardiometabolic risk factors in a Japanese population: the INTERMAP/INTERLIPID Study. Eur J Nutr. 2016;55(4):1515-24. doi:10.1007/s00394-015-0969-z | | X
717 | Nakamura Y, Okuda N, Okamura T. Low-carbohydrate diets and cardiovascular and total mortality in Japanese: a 29-year follow-up of NIPPON DATA80. Br J Nutr. 2014;112(6):916-924. doi:10.1017/S0007114514001627 | | X
718 | Namayandeh SM, Kaseb F, Lesan S. Olive and sesame oil effect on lipid profile in hypercholesterolemic patientswhich better?. Int J Prev Med. 2013;4(9):1059-62. | | | | Health Status
719 | Navas-Carretero S, Zulet MA, Abete I, Planes J, Avellaneda A, Martinez JA. Influence on health markers of the regular consumption of anew meat product designed with an optimized nutritional profile. Annals of Nutrition and Metabolism. 2013. 63(Suppl 1):1678. doi:10.1159/000354245 | | | | Publication Status
720 | Negele L, Schneider B, Ristl R, et al. Effect of a low-fat diet enriched either with rapeseed oil or sunflower oil on plasma lipoproteins in children and adolescents with familial hypercholesterolaemia. Results of a pilot study. Eur J Clin Nutr. 2015;69(3):337-43. doi:10.1038/ejcn.2014.234 | | X | | Health Status
721 | Nejatinamini S, Ataie-Jafari A, Ghasemian A, et al. Burden of ischemic heart disease attributable to low omega-3 fatty acids intake in Iran: findings from the Global Burden of Disease Study 2010. J Tehran Heart Cent. 2016;11(1):21-9. | X
722 | Nettleton JA, Brouwer IA, Geleijnse JM, Hornstra G. Saturated fat consumption and risk of coronary heart disease and ischemic stroke: a science update. Ann Nutr Metab. 2017;70(1):26-33. doi:10.1159/000455681 | X
723 | Neuhouser ML, Howard B, Lu J, et al. A low-fat dietary pattern and risk of metabolic syndrome in postmenopausal women: the Women’s Health Initiative. Metabolism. 2012;61(11):1572-81. doi:10.1016/j.metabol.2012.04.007 | | X
724 | Neville MM, Geppert J, Min Y, Grimble G, Crawford MA, Ghebremeskel K. Dietary fat intake body composition and blood lipids of university men and women. Nutr Health. 2012;21(3):173-85. doi:10.1177/0260106012467242 | X
725 | Ng CPS, Kwok JSL, Zhou J, Cheung PYB, Tzang LCH, Sundaram S. Effect of whole grains and unsaturated fatty acids dietary intervention on health in Hong Kong overweight population. Gut. 2018;67(Suppl 2):A71. doi:10.1136/gutjnl-2018-IDDFabstracts.153 | | | | Publication Status
726 | Nicklas JM, Sacks FM, Smith SR, et al. Effect of dietary composition of weight loss diets on high-sensitivity c-reactive protein: the Randomized POUNDS LOST trial. Obesity (Silver Spring). 2013;21(4):681-9. doi:10.1002/oby.20072 | | X
727 | Nicklas TA, O’Neil CE, Fulgoni VL 3rd. Snacking patterns diet quality, and cardiovascular risk factors in adults. BMC Public Health. 2014;14:388. doi:10.1186/1471-2458-14-388 | X | | X
728 | Nieman DC, Gillitt N, Jin F, et al. Chia seed supplementation and disease risk factors in overweight women: a metabolomics investigation. J Altern Complement Med. 2012;18(7):700-8. doi:10.1089/acm.2011.0443 | | X
729 | Nieman KM, Maki KC, Palacios OM, Lindner E, Huebner M, Sorce J. Replacement of refined carbohydrates with a combination of egg protein and unsaturated fatty acids: effects on lipoprotein particle concentrations and LDL peak size in adults with elevated triglycerides. FASEB journal. 2017;31(Suppl 1). | | | | Publication Status
730 | Niinikoski H, Pahkala K, Viikari J, et al. The STRIP Study: long-Term Impact of a Low Saturated Fat/Low Cholesterol Diet. Current cardiovascular risk reports. 2014;8(11):1- 7. doi:10.1007/s12170-014-0410-9 | X | | | Duplicate data
731 | Niinikoski H, Viikari J, Ronnemaa T, et al. Prospective randomized trial of low-saturated-fat, low-cholesterol diet during the first 3 years of life. The STRIP baby project. Circulation. 1996. 94(6):1386-93. doi:10.1161/01.cir.94.6.1386 | | | | Duplicate data
732 | Nilsen R, Hostmark AT, Haug A, Skeie S. Effect of a high intake of cheese on cholesterol and metabolic syndrome: results of a randomized trial. Food Nutr Res. 2015;59:27651. doi:10.3402/fnr.v59.27651 | | X
733 | Niswender KD, Fazio S, Gower BA, Silver HJ. Balanced high fat diet reduces cardiovascular risk in obese women although changes in adipose tissue, lipoproteins, and insulin resistance differ by race. Metabolism. 2018;82:125-134. doi:10.1016/j.metabol.2018.01.020 | X | X
734 | Nordgren TM, Anderson Berry A, Van Ormer M, et al. Omega-3 fatty acid supplementation, pro-resolving mediators, and clinical outcomes in maternal-infant pairs. Nutrients. 2019;11(1). pii: E98. doi:10.3390/nu11010098 | | X | X
735 | Normia J, Laitinen K, Isolauri E, Poussa T, Jaakkola J, Ojala T. Impact of intrauterine and post-natal nutritional determinants on blood pressure at 4 years of age. J Hum Nutr Diet. 2013;26(6):544-52. doi:10.1111/jhn.12115 | X | X
736 | Noto D, Fayer F, Cefalu AB, et al. Myristic acid is associated to low plasma HDL cholesterol levels in a Mediterranean population and increases HDL catabolism by enhancing HDL particles trapping to cell surface proteoglycans in a liver hepatoma cell model. Atherosclerosis. 2016;246:50-6. doi:10.1016/j.atherosclerosis.2015.12.036 | | X
737 | Nybacka A, Hellstrom PM, Hirschberg AL. Increased fibre and reduced trans fatty acid intake are primary predictors of metabolic improvement in overweight polycystic ovary syndrome-substudy of randomized trial between diet, exercise and diet plus exercise for weight control. Clin Endocrinol (Oxf). 2017;87(6):680-688. doi:10.1111/cen.13427 | | X
738 | Nykanen T, Pihlainen K, Santtila M, Vasankari T, Fogelholm M, Kyrolainen H. Diet macronutrient composition, physical activity, and body composition in soldiers during 6 months deployment. Mil Med. 2019;184(3-4):e231-e237. doi:10.1093/milmed/usy232 | | | X
739 | O’Connor J, Steinbeck K, Hill A, et al. Evaluation of a community-based weight management program for overweight and obese adolescents: the Loozit study. Nutrition & Dietetics. 2008. 65(2):121-127. | | X
740 | O’Connor LE, Paddon-Jones D, Wright AJ, Campbell WW. A Mediterranean-style eating pattern with lean unprocessed red meat has cardiometabolic benefits for adults who are overweight or obese in a randomized, crossover, controlled feeding trial. American Journal of Clinical Nutrition. 2018;108(1):33-40. doi:10.1093/ajcn/nqy075 | | X
741 | Okburan G, Mercanligil SM. Effects of walnut consumption on blood lipids and lipoproteins in hyperlipidemic individuals. Clinical Nutrition. 2016. 35(Suppl 1):S83. doi:10.1016/S0261-5614(16)30448-4 | | | | Publication Status
742 | Oliveira-de-Lira L, Santos EMC, de Souza RF, et al. Supplementation-dependent effects of vegetable oils with varying fatty acid compositions on anthropometric and biochemical parameters in obese women. Nutrients. 2018;10(7): pii: E932. doi:10.3390/nu10070932 | | X
743 | Oliver MF. Free fatty acids and acute coronary syndromes--the history. QJM. 2011;104(7):625-7. doi:10.1093/qjmed/hcr016 | X
744 | Omega-3 fatty acid supplements and cardiovascular disease. Drug Ther Bull. 2018;56(4):39. doi:10.1136/dtb.2018.4.0606 | X
745 | O’Neil CE, Nicklas TA, Myers L, Johnson CC, Berenson GS. Cardiovascular risk factors and behavior lifestyles of young women: implications from findings of the Bogalusa Heart Study. Am J Med Sci. 1997. 314(6):385-95. doi:10.1097/00000441-199712000-00005 | X
746 | Oranta O, Pahkala K, Ruottinen S, et al. Infancy-onset dietary counseling of low-saturated-fat diet improves insulin sensitivity in healthy adolescents 15-20 years of age: the Special Turku Coronary Risk Factor Intervention Project (STRIP) study. Diabetes Care. 2013;36(10):2952-9. doi:10.2337/dc13-0361 | | | X
747 | Orem A, Yucesan FB, Orem C, et al. Hazelnut-enriched diet improves cardiovascular risk biomarkers beyond a lipid-lowering effect in hypercholesterolemic subjects. J Clin Lipidol. 2013;7(2):123-31. doi:10.1016/j.jacl.2012.10.005 | | | | Health Status
748 | Ortega JF, Morales-Palomo F, Fernandez-Elias V, et al. Dietary supplementation with omega-3 fatty acids and oleate enhances exercise training effects in patients with metabolic syndrome. Ob. 2016;24(8):1704-11. doi:10.1002/oby.21552 | | X
749 | Ortega RM, Requejo AM, Navia B, et al. Effect of saturated fatty acid consumption on energy and nutrient intake and blood lipid levels in preschool children. Ann Nutr Metab. 2001. 45(3):121-7. doi:10.1159/000046717 | X
750 | Ortega RM, Requejo AM, Navia B, et al. The consumption of milk products in a group of pre-school children: influence on serum lipid profile. Nutrition Research. 2000. 20(6):779-790. doi:10.1016/S0271-5317(00)00175-5 | | X
751 | Ortiz RM, Garcia S, Kim AD. Is almond consumption more effective than reduced dietary saturated fat at decreasing plasma total cholesterol and LDL-c Levels? A theoretical approach. J Nutr Metab. 2012;2012:265712. doi:10.1155/2012/265712 | X
752 | O’Sullivan TA, Ambrosini GL, Mori TA, Beilin LJ, Oddy WH. Omega-3 Index correlates with healthier food consumption in adolescents and with reduced cardiovascular disease risk factors in adolescent boys. Lipids. 2011;46(1):59-67. doi:10.1007/s11745-010-3499-8 | X | X
753 | O’Sullivan TA, Bremner AP, Mori TA, et al. Regular fat and reduced fat dairy products show similar associations with markers of adolescent cardiometabolic health. Nutrients. 2016;8(1): pii: E22. doi:10.3390/nu8010022 | | X
754 | Otsuka R, Tange C, Nishita Y, et al. Fish and meat intake, serum eicosapentaenoic acid and docosahexaenoic acid levels, and mortality in community-dwelling Japanese older persons. Int J Environ Res Public Health. 2019;16(10): pii: E1806. doi:10.3390/ijerph16101806 | | | X
755 | Otten J, Mellberg C, Ryberg M, et al. Strong and persistent effect on liver fat with a Paleolithic diet during a two-year intervention. Int J Obes (Lond). 2016;40(5):747-53. doi:10.1038/ijo.2016.4 | | X | X
756 | Oudin A, Wennberg M. Fish consumption and ischemic stroke in southern Sweden. Nutr J. 2011;10109. doi:10.1186/1475-2891-10-109 | | X
757 | Oyri LKL, Narverud I, Bogsrud MP, et al. Postprandial changes in gene expression of cholesterol influx and efflux mediators after intake of SFA compared with n-6 PUFA in subjects with and without familial hypercholesterolaemia: secondary outcomes of a randomised controlled trial. J Nutr Sci. 2019;8:e27. doi:10.1017/jns.2019.25 | X | | X
758 | Pagliai G, Russo E, Niccolai E, et al. Influence of a 3-month low-calorie Mediterranean diet compared to the vegetarian diet on human gut microbiota and SCFA: the CARDIVEG Study. Eur J Nutr. 2019;doi:10.1007/s00394-019-02050-0 | | | X
759 | Pahkala K, Hietalampi H, Laitinen TT, et al. Ideal cardiovascular health in adolescence: effect of lifestyle intervention and association with vascular intima-media thickness and elasticity (the Special Turku Coronary Risk Factor Intervention Project for Children [STRIP] study). Circulation. 2013;127(21):2088-96. doi:10.1161/circulationaha.112.000761 | | X | X
760 | Palazhy S, Kamath P, Rajesh PC, Vaidyanathan K, Nair SK, Vasudevan DM. Composition of plasma and atheromatous plaque among coronary artery disease subjects consuming coconut oil or sunflower oil as the cooking medium. J Am Coll Nutr. 2012;31(6):392-6. doi:10.1080/07315724.2012.10720464 | | | X | Country
761 | Paletas K, Athanasiadou E, Sarigianni M, et al. The protective role of the Mediterranean diet on the prevalence of metabolic syndrome in a population of Greek obese subjects. J Am Coll Nutr. 2010;29(1):41-5. doi:10.1080/07315724.2010.10719815 | X
762 | Pałkowska E, Bartnikowska E, Owsiak D. The use of low-caloric diet with modified fatty acids pool in the therapy of the metabolic syndrome. Rocz Panstw Zakl Hig. 2012;63(2):163- 169. | | | | Language
763 | Pang D, Allman-Farinelli MA, Wong T, Barnes R, Kingham KM. Replacement of linoleic acid with alpha-linolenic acid does not alter blood lipids in normolipidaemic men. Br J Nutr. 1998. 80(2):163-7. | | | | Age of participants at intervention or exposure
764 | Pang SJ, Jia SS, Man QQ, et al. Dietary cholesterol in the elderly Chinese population: an analysis of CNHS 2010-2012. Nutrients. 2017;9(9). pii: E934. doi:10.3390/nu9090934 | X
765 | Paniagua JA, Perez-Martinez P, Gjelstad IM, et al. A low-fat high-carbohydrate diet supplemented with long-chain n-3 PUFA reduces the risk of the metabolic syndrome. Atherosclerosis. 2011;218(2):443-50. doi:10.1016/j.atherosclerosis.2011.07.003 | | | | Duplicate data
766 | Paoli A, Cenci L, Grimaldi KA. Effect of ketogenic Mediterranean diet with phytoextracts and low carbohydrates/high-protein meals on weight, cardiovascular risk factorsbody composition and diet compliance in Italian council employees. Nutr J. 2011;10112. doi:10.1186/1475-2891-10-112 | | X
767 | Papadaki A, Martinez-Gonzalez MA, Alonso-Gomez A, et al. Mediterranean diet and risk of heart failure: results from the PREDIMED randomized controlled trial. Eur J Heart Fail. 2017;19(9):1179-1185. doi:10.1002/ejhf.750 | | X
768 | Papandreou D, Karabouta Z, Rousso I. Are dietary cholesterol intake and serum cholesterol levels related to nonalcoholic Fatty liver disease in obese children?. Cholesterol. 2012;doi: 10.1155/2012/572820 | X
769 | Paquet C, Propsting SL, Daniel M. Total n-3 fatty acid and SFA intakes in relation to insulin resistance in a Canadian First Nation at risk for the development of type 2 diabetes. Public Health Nutr. 2014;17(6):1337-41. doi:10.1017/s1368980013000542 | X | | X
770 | Park BS, Ryu CM, Ahn YS, Park SO. The consumption of low animal food with low n-6/n-3 ratio reduce LDL cholesterol in humans. Res J Med Sci. 2012;6(3):107-112. doi:10.3923/rjmsci.2012.107.112 | | | X | Study Duration
771 | Park JE, Miller M, Rhyne J, Wang Z, Hazen SL. Differential effect of short-term popular diets on TMAO and other cardio-metabolic risk markers. Nutr Metab Cardiovasc Dis. 2019;29(5):513-517. doi:10.1016/j.numecd.2019.02.003 | | | X
772 | Park JK, Koehler KM. Probabilistic quantitative assessment of coronary heart disease risk from dietary exposure to industrially-produced trans fatty acids in partially hydrogenated oils. Toxicol Sci. 2019;171(1):213-224. doi:10.1093/toxsci/kfz170 | X | X
773 | Park S, Kim DS, Kang S. Carrying minor allele of FADS1 and haplotype of FADS1 and FADS2 increased the risk of metabolic syndrome and moderate but not low fat diets lowered the risk in two Korean cohorts. Eur J Nutr. 2019;58(2):831-842. doi:10.1007/s00394-018-1719-9 | X
774 | Park Y, Oh SH, Rhee MY. Association between 24-hour ambulatory blood pressure and erythrocyte n-3 polyunsaturated fatty acids in Korean subjects with hypertension. Nutr Res. 2010;30(12):807-14. doi:10.1016/j.nutres.2010.09.013 | X
775 | Parletta N, Zarnowiecki D, Cho J, et al. A Mediterranean-style dietary intervention supplemented with fish oil improves diet quality and mental health in people with depression: a randomized controlled trial (HELFIMED). Nutr Neurosci. 2019;22(7):474-487. doi:10.1080/1028415x.2017.1411320 | | | X
776 | Pavithra N, Bannikoppa PS, Uthappa S, Kurpad AV, Mani I. Plasma fatty acid composition and estimated desaturase activities reflect dietary patterns in subjects with metabolic syndrome. Indian J Clin Biochem. 2018;33(3):290-296. doi:10.1007/s12291-017-0674-1 | | X | | Country
777 | Pawelczyk T, Trafalska E, Kotlicka-Antczak M, Pawelczyk A. The association between polyunsaturated fatty acid consumption and the transition to psychosis in ultra-high risk individuals. Prostaglandins Leukot Essent Fatty Acids. 2016;108:30-7. doi:10.1016/j.plefa.2016.03.010 | | | X | Health Status
778 | Pegington M, Evans DG, Howell A, et al. Lifestyle behaviours and health measures of women at increased risk of breast cancer taking chemoprevention. Eur J Cancer Prev. 2019;28(6):500-506. doi:10.1097/cej.0000000000000493 | | X | X
779 | Pei R, DiMarco DM, Putt KK, et al. Low-fat yogurt consumption reduces biomarkers of chronic inflammation and inhibits markers of endotoxin exposure in healthy premenopausal women: a randomised controlled trial. Br J Nutr. 2017;118(12):1043-1051. doi:10.1017/s0007114517003038 | | X | X
780 | Pellizzer AM, Straznicky NE, Lim S, Kamen PW, Krum H. Reduced dietary fat intake increases parasympathetic activity in healthy premenopausal women. Clin Exp Pharmacol Physiol. 1999. 26(8):656-60. doi:10.1046/j.1440-1681.1999.03103.x | | X
781 | Penedo LA, Nunes JC, Gama MA, Leite PE, Quirico-Santos TF, Torres AG. Intake of butter naturally enriched with cis9,trans11 conjugated linoleic acid reduces systemic inflammatory mediators in healthy young adults. J Nutr Biochem. 2013;24(12):2144-51. doi:10.1016/j.jnutbio.2013.08.006 | | X | X
782 | Perelman D, Coghlan N, Lamendola C, Carter S, Abbasi F, McLaughlin T. Substituting poly- and mono-unsaturated fat for dietary carbohydrate reduces hyperinsulinemia in women with polycystic ovary syndrome. Gynecol Endocrinol. 2017;33(4):324-327. doi:10.1080/09513590.2016.1259407 | | | X | Study Duration
783 | Perez-Cornago A, Brennan L, Ibero-Baraibar I, et al. Metabolomics identifies changes in fatty acid and amino acid profiles in serum of overweight older adults following a weight loss intervention. J Physiol Biochem. 2014;70(2):593-602. doi:10.1007/s13105-013-0311-2 | | X | X
784 | Perez-Heras AM, Mayneris-Perxachs J, Cofan M, et al. Long-chain n-3 PUFA supplied by the usual diet decrease plasma stearoyl-CoA desaturase index in non-hypertriglyceridemic older adults at high vascular risk. Clin Nutr. 2018;37(1):157-162. doi:10.1016/j.clnu.2016.11.009 | | | X
785 | Perichart-Perera O, Balas-Nakash M, Rodriguez-Cano A, et al. Correlates of dietary energy sources with cardiovascular disease risk markers in Mexican school-age children. J Am Diet Assoc. 2010;110(2):253-60. doi:10.1016/j.jada.2009.10.031 | X | X
786 | Perona JS, Covas MI, Fito M, Cabello-Moruno R, Aros F, Corella D, Ros E, Garcia M, Estruch R, Martinez-Gonzalez MA, Ruiz-Gutierrez V. Reduction in systemic and VLDL triacylglycerol concentration after a 3-month Mediterranean-style diet in high-cardiovascular-risk subjects. J Nutr Biochem. 2010;21(9):892-8. doi:10.1016/j.jnutbio.2009.07.005 | | X
787 | Perry AC, Tremblay LM, Signorile JF, Kaplan TA, Miller PC. Fitness diet and coronary risk factors in a sample of southeastern U.S. children. Appl Human Sci. 1997. 16(4):133-41. | X | X
788 | Pertiwi K, Kok DE, Wanders AJ, de Goede J, Zock PL, Geleijnse JM. Circulating n-3 fatty acids and linoleic acid as indicators of dietary fatty acid intake in post-myocardial infarction patients. Nutr Metab Cardiovasc Dis. 2019;29(4):343-350. doi:10.1016/j.numecd.2018.12.010 | X | | | Health Status
789 | Petrogianni M, Grammatikaki E, Kalogeropoulos N, et al. Additional benefit in CVD risk indices derived from the consumption of fortified milk when combined with a lifestyle intervention. Public Health Nutr. 2014;17(2):440-9. doi:10.1017/s1368980012005265 | | X | | Health Status
790 | Phillips CM, Kesse-Guyot E, Ahluwalia N, et al. Dietary fat abdominal obesity and smoking modulate the relationship between plasma complement component 3 concentrations and metabolic syndrome risk. Atherosclerosis. 2012;220(2):513-9. doi:10.1016/j.atherosclerosis.2011.11.007 | | X | X
791 | Pieters DJ, Zock PL, Fuchs D, Mensink RP. Effect of alpha-linolenic acid on 24-h ambulatory blood pressure in untreated high-normal and stage I hypertensive subjects. Br J Nutr. 2019;121(2):155-163. doi:10.1017/s0007114518003094 | | | X
792 | Pignitter M, Lindenmeier M, Andersen G, et al. Effect of 1- and 2-month high-dose alpha-linolenic acid treatment on (13) C-labeled alpha-linolenic acid incorporation and conversion in healthy subjects. Mol Nutr Food Res. 2018;62(20):e1800271. doi:10.1002/mnfr.201800271 | | | X
793 | Pihlajamaki JA, Schwab U, Kaminska D, et al. Dietary polyunsaturated fatty acids and the Pro12Ala polymorphisms of PPARG regulate serum lipids through divergent pathways: a randomised crossover clinical trial. Diabetologia. 2013. 56(Suppl 1):S154. doi:10.1007/s00125-013-3012-z | | | | Publication Status
794 | Pilis K, Pilis A, Stec K, et al. Three-year chronic consumption of low-carbohydrate diet impairs exercise performance and has a small unfavorable effect on lipid profile in middle-aged men. Nutrients. 2018;10(12):pii:E1914. doi:10.3390/nu10121914 | X | X
795 | Pinto X, Fanlo-Maresma M, Corbella E, et al. A Mediterranean diet rich in extra-virgin olive oil is associated with a reduced prevalence of nonalcoholic fatty liver disease in older individuals at high cardiovascular risk. J Nutr. 2019;149(11):1920-1929. doi:10.1093/jn/nxz147 | | X | X
796 | Pintus S, Murru E, Carta G, et al. Sheep cheese naturally enriched in alpha-linolenic, conjugated linoleic and vaccenic acids improves the lipid profile and reduces anandamide in the plasma of hypercholesterolaemic subjects. Br J Nutr. 2013;109(8):1453-62. doi:10.1017/s0007114512003224 | | X
797 | Pisinger C, Jacobsen RK, Jørgensen T. Final results from one of world’s largest population-based randomized interventions on lifestyle. The Inter99 study. Circulation. 2013;127(12) | | | | Publication Status
798 | Polley KR, Oswell NJ, Pegg RB, Paton CM, Cooper JA. A 5-day high-fat diet rich in cottonseed oil improves cholesterol profiles and triglycerides compared to olive oil in healthy men. Nutr Res. 2018;60:43-53. doi:10.1016/j.nutres.2018.09.001 | | | X | Study Duration
799 | Polychronopoulos E, Pounis G, Bountziouka V, et al. Dietary meat fats and burden of cardiovascular disease risk factors, in the elderly: a report from the MEDIS study. Lipids Health Dis. 2010;9:30. doi:10.1186/1476-511x-9-30 | X
800 | Porkka KV, Raitakari OT, Leino A, et al. Trends in serum lipid levels during 1980-1992 in children and young adults. The Cardiovascular Risk in Young Finns Study. Am J Epidemiol. 1997. 146(1):64-77. doi:10.1093/oxfordjournals.aje.a009192 | X
801 | Praagman J, Franco OH, Ikram MA, et al. Dairy products and the risk of stroke and coronary heart disease: the Rotterdam Study. Eur J Nutr. 2015;54(6):981-90. doi:10.1007/s00394-014-0774-0 | | X
802 | Pranger IG, Corpeleijn E, Muskiet FAJ, Kema IP, Singh-Povel C, Bakker SJL. Circulating fatty acids as biomarkers of dairy fat intake: data from the lifelines biobank and cohort study. Biomarkers. 2019;24(4):360-372. doi:10.1080/1354750x.2019.1583770 | X | X
803 | Prentice RL, Aragaki AK, Howard BV, et al. Low-fat dietary pattern among postmenopausal women influences long-term cancer cardiovascular disease and diabetes outcomes. J Nutr. 2019;149(9):1565-1574. doi:10.1093/jn/nxz107 | | X
804 | Prentice RL, Aragaki AK, Van Horn L, et al. Low-fat dietary pattern and cardiovascular disease: results from the Women’s Health Initiative randomized controlled trial. Am J Clin Nutr. 2017;106(1):35-43. doi:10.3945/ajcn.117.153270 | | X
805 | Properzi C, Sullivan T, Sherriff J, et al. Ad libitum Mediterranean and low fat diets both significantly reduce hepatic steatosis: a randomized controlled trial. Hepatol Int. 2018;12(2):S232. doi:10.1007/s12072-018-9852-3 | | | | Publication Status
806 | Pu S, Rodriguez-Perez C, Ramprasath VR, Segura-Carretero A, Jones PJ. Dietary high oleic canola oil supplemented with docosahexaenoic acid attenuates plasma proprotein convertase subtilisin kexin type 9 (PCSK9) levels in participants with cardiovascular disease risk: a randomized control trial. Vascul Pharmacol. 2016;87:60-65. doi:10.1016/j.vph.2016.06.007 | | | X | Duplicate data
807 | Quintanilha BJ, Pinto Ferreira LR, Ferreira FM, Neto EC, Sampaio GR, Rogero MM. Circulating plasma microRNAs dysregulation and metabolic endotoxemia induced by a high-fat high-saturated diet. Clin Nutr. 2019;39(2):554-562. doi:10.1016/j.clnu.2019.02.042 | | X | X
808 | Quivers ES, Driscoll DJ, Garvey CD, et al. The effects of diet on serum cholesterol in children. Ann N Y Acad Sci. 1991. 623:133-4. doi:10.1111/j.1749-6632.1991.tb43724.x | X | X
809 | Raatz SK, Johnson LK, Rosenberger TA, Picklo MJ. Twice weekly intake of farmed Atlantic salmon (Salmo salar) positively influences lipoprotein concentration and particle size in overweight men and women. Nutr Res. 2016;36(9):899-906. doi:10.1016/j.nutres.2016.06.011 | | X
810 | Radtke T, Schmid A, Trepp A, et al. Short-term effects of trans fatty acids from ruminant and industrial sources on surrogate markers of cardiovascular risk in healthy men and women: a randomized, controlled, double-blind trial. Eur J Prev Cardiol. 2017;24(5):534-543. doi:10.1177/2047487316680691 | | X
811 | Raitakari OT, Porkka KV, Rasanen L, Ronnemaa T, Viikari JS. Clustering and six year cluster-tracking of serum total cholesterol, HDL-cholesterol and diastolic blood pressure in children and young adults. The Cardiovascular Risk in Young Finns Study. J Clin Epidemiol. 1994. 47(10):1085-93. doi:10.1016/0895-4356(94)90094-9 | X | | X
812 | Raitakari OT, Porkka KV, Rasanen L, Viikari JS. Relations of life-style with lipids, blood pressure and insulin in adolescents and young adults. The Cardiovascular Risk in Young Finns Study. Atherosclerosis. 1994. 111(2):237-46. doi:10.1016/0021-9150(94)90098-1 | X
813 | Rajaie S, Azadbakht L, Khazaei M, Esmaillzadeh A. Effects of a moderately-restricted carbohydrate diet on cardiovascular risk factors among women with metabolic syndrome. Journal of Isfahan Medical School. 2012;29(171). | | | | Language
814 | Rajaie S, Azadbakht L, Khazaei M, Sherbafchi M, Esmaillzadeh A. Moderate replacement of carbohydrates by dietary fats affects features of metabolic syndrome: a randomized crossover clinical trial. Nutrition. 2014;30(1):61-8. doi:10.1016/j.nut.2013.06.011 | | X
815 | Rajaram S, Yip EL, Reghunathan R, Mohan S, Sabate J. Effect of altering dietary n-6: n-3 polyunsaturated fatty acid ratio with plant and marine-based supplement on biomarkers of bone turnover in healthy adults. Nutrients. 2017;9(10): pii: E1162. doi:10.3390/nu9101162 | | | X
816 | Rajendiran E, She Y, Tessier-Grenier M, et al. Apolipoprotein E variants and sex modify the action of dairy fat intake on plasma HDL-cholesterol and adiponectin concentration. J Nutrigenet Nutrigenomics. 2017;10(3- 4):114. doi:10.1159/000480052 | | | | Publication Status
817 | Ramel A, Martinez JA, Kiely M, Bandarra NM, Thorsdottir I. Moderate consumption of fatty fish reduces diastolic blood pressure in overweight and obese European young adults during energy restriction. Nutrition. 2010;26(2):168-74. doi:10.1016/j.nut.2009.04.002 | | | X
818 | Ramos-Lopez O, Riezu-Boj JI, Milagro FI, Goni L, Cuervo M, Martinez JA. Differential lipid metabolism outcomes associated with ADRB2 gene polymorphisms in response to two dietary interventions in overweight/obese subjects. Nutr Metab Cardiovasc Dis. 2018;28(2):165-172. doi:10.1016/j.numecd.2017.11.006 | | X
819 | Ramprasath VR, Jones PJ, Buckley DD, Woollett LA, Heubi JE. Decreased plasma cholesterol concentrations after PUFA-rich diets are not due to reduced cholesterol absorption/synthesis. Lipids. 2012;47(11):1063-71. doi:10.1007/s11745-012-3708-8 | | | | Study Duration
820 | Ramsden CE, Zamora D, Faurot K, Majchrzak S, Hibbeln J. The Sydney diet heart study: a randomised controlled trial of linoleic acid for secondary prevention of coronary heart disease and death. FASEB journal. 2013;27(Suppl 1). | | | | Publication Status
821 | Ramsden CE, Zamora D, Leelarthaepin B, et al. Use of dietary linoleic acid for secondary prevention of coronary heart disease and death: Evaluation of recovered data from the Sydney Diet Heart Study and updated meta-analysis. BMJ. 2013. 346(7894):e8707. doi:10.1136/bmj.e8707 | | | | Health Status
822 | Ramsden CE, Zamora D, Majchrzak-Hong S, et al. Re-evaluation of the traditional diet-heart hypothesis: analysis of recovered data from Minnesota Coronary Experiment (1968-73). BMJ. 2016;353:i1246. doi:10.1136/bmj.i1246 | | | | Health Status
823 | Rancourt-Bouchard M, Gigleux I, Guay V, et al. Effects of regular-fat and low-fat dairy consumption on daytime ambulatory blood pressure and other cardiometabolic risk factors: a randomized controlled feeding trial. Am J Clin Nutr. 2019;111(1):42-51. doi:10.1093/ajcn/nqz251 | | X
824 | Ras R, Demonty I, Zebregs Y, Quadt F, Olsson J, Trautwein E. The combined effect on blood lipids of plant sterols and different low doses of omega-3 fatty acids. Atherosclerosis. 2014. 235(2):e112. doi:10.1016/j.atherosclerosis.2014.05.304 | | | | Publication Status
825 | Rashid NA, Nawi AM, Khadijah S. Exploratory analysis of traditional risk factors of ischemic heart disease (IHD) among predominantly Malay Malaysian women. BMC Public Health. 2019;19(Suppl 4):545. doi:10.1186/s12889-019-6855-5 | X | X
826 | Rask-Nissila L, Jokinen E, Viikari J, et al. Impact of dietary intervention, sex, and apolipoprotein E phenotype on tracking of serum lipids and apolipoproteins in 1- to 5-year-old children: the Special Turku Coronary Risk Factor Intervention Project (STRIP). Arterioscler Thromb Vasc Biol. 2002;22(3):492-8. doi:10.1161/hq0302.104516 | | | | Duplicate data
827 | Rathnayake KM, Weech M, Jackson KG, Lovegrove JA. Impact of the Apolipoprotein E (epsilon) genotype on cardiometabolic risk markers and responsiveness to acute and chronic dietary fat manipulation. Nutrients. 2019;11(9): pii: E2044. doi:10.3390/nu11092044 | | X
828 | Raziani F, Ebrahimi P, Engelsen SB, Astrup A, Raben A, Tholstrup T. Consumption of regular-fat vs reduced-fat cheese reveals gender-specific changes in LDL particle size - a randomized controlled trial. Nutrition & Metabolism. 2018;15(61). doi:10.1186/s12986-018-0300-0 | | X
829 | Razny, Polus, Wnek, et al. The effect of N-3 PUFA supplementation on postprandial triglycerides and insulin in obesity. The BIOCLAIMS study. Obesity facts. 2014. 7(Suppl 1)798- 99. doi:10.1159/000363668 | | | | Publication Status
830 | Razquin C, Sanchez-Tainta A, Salas-Salvado J, et al. Dietary energy density and body weight changes after 3 years in the PREDIMED study. Int J Food Sci Nutr. 2017;68(7):865-872. doi:10.1080/09637486.2017.1295028 | | | X
831 | Redondo N, García-González N, Diaz-Prieto LE, et al. Effects of ewe’s milk yogurt (whole and semi-skimmed) and cow’s milk yogurt on inflammation markers and gut microbiota of subjects with borderline-high plasma cholesterol levels: a crossover study. Eur J Nutr. 2019;58(3):1113-1124. doi:10.1007/s00394-018-1626-0 | | X
832 | Reeves JL, Otahal P, Magnussen CG, et al. DHA mediates the protective effect of fish consumption on new episodes of depression among women. Br J Nutr. 2017;118(9):743-749. doi:10.1017/s0007114517002768 | | | X
833 | Reidlinger DP, Darzi J, Hall WL, et al. The effectiveness of an integrated dietary intervention compared with an average UK diet in reducing cardiovascular disease risk factors in older men and women aged 40 to 70 years: the CRESSIDA Study. Proceedings of the nutrition society. 2013;72(OCE4):E249. doi:10.1017/S0029665113002747 | | | | Publication Status
834 | Reidlinger DP, Darzi J, Hall WL, et al. How effective are current dietary guidelines for cardiovascular disease prevention in healthy middle-aged and older men and women? A randomized controlled trial. Am J Clin Nutr. 2015;101(5):922-930. doi:10.3945/ajcn.114.097352 | | X
835 | Reiner MF, Stivala S, Limacher A, et al. Omega-3 fatty acids predict recurrent venous thromboembolism or total mortality in elderly patients with acute venous thromboembolism. J Thromb Haemost. 2017;15(1):47-56. doi:10.1111/jth.13553 | | X | | Health Status
836 | Reis RS, Dalle Molle R, Machado TD, et al. Impulsivity-based thrifty eating phenotype and the protective role of n-3 PUFAs intake in adolescents. Transl Psychiatry. 2016;15:6e755. doi:10.1038/tp.2016.16 | | X | X
837 | Renu M, Khushbu A. Diet and lipid profile of menopausal women as risk factors of cardiovascular disease. Indian Journal of Public Health Research and Development. 2014;5(3):104-108. doi:10.5958/0976-5506.2014.00283.6 | | | | Country
838 | Retterstol K, Svendsen M, Narverud I, Holven KB. Effect of low carbohydrate high fat diet on LDL cholesterol and gene expression in normal-weight, young adults: a randomized controlled study. Atherosclerosis. 2018;279:52-61. doi:10.1016/j.atherosclerosis.2018.10.013 | | X
839 | Riestra P, Lopez-Simon L, Ortega H, et al. Fat intake influences the effect of the hepatic lipase C-514T polymorphism on HDL-cholesterol levels in children. Exp Biol Med (Maywood). 2009. 234(7):744-9. doi:10.3181/0812-rm-373 | X
840 | Rietman A, Schwarz J, Blokker BA, et al. Increasing protein intake modulates lipid metabolism in healthy young men and women consuming a high-fat hypercaloric diet. J Nutr. 2014;144(8):1174-80. doi:10.3945/jn.114.191072 | | X
841 | Rix TA, Joensen AM, Riahi S, et al. A U-shaped association between consumption of marine n-3 fatty acids and development of atrial fibrillation/atrial flutter - A Danish cohort study. Europace. 2014;16(11):1554-1561. doi:10.1093/europace/euu019 | | | X
842 | Roberge JB, Van Hulst A, Barnett TA, et al. Lifestyle habits, dietary factors, and the metabolically unhealthy obese phenotype in youth. J Pediatr. 2019;46-52.e1. doi:10.1016/j.jpeds.2018.08.063 | | | X
843 | Rock CL, Flatt SW, Barkai HS, Pakiz B, Heath DD. Walnut consumption in a weight reduction intervention: effects on body weight, biological measures blood pressure and satiety. Nutr J. 2017;16(1):76. doi:10.1186/s12937-017-0304-z | | X
844 | Rodriguez-Perez C, Ramprasath VR, Pu S, et al. Docosahexaenoic acid attenuates cardiovascular risk factors via a decline in proprotein convertase subtilisin/kexin type 9 (PCSK9) plasma levels. Lipids. 2016;51(1):75-83. doi:10.1007/s11745-015-4099-4 | | | | Duplicate data
845 | Rogers IS, Emmett PM. Fat content of the diet among preschool children in southwest Britain: II. relationship with growth blood lipids and iron status. Pediatrics. 2001. 108(3):E49. doi:10.1542/peds.108.3.e49 | | X
846 | Rogers TS, Seehusen DA. Omega-3 Fatty Acids and Cardiovascular Disease. Am Fam Physician. 2018;97(9):562-564. | X
847 | Rogerson D, Macas D, Milner M, Liu Y, Klonizakis M. Contrasting effects of short-term Mediterranean and vegan diets on microvascular function and cholesterol in younger adults: a comparative pilot study. Nutrients. 2018;10(12): pii: E1897. doi:10.3390/nu10121897 | | X
848 | Roncero-Ramos I, Rangel-Zuniga OA, Lopez-Moreno J, et al. Mediterranean diet, glucose homeostasis, and inflammasome genetic variants: The CORDIOPREV Study. Mol Nutr Food Res. 2018;62(9):e1700960. doi:10.1002/mnfr.201700960 | | | | Health Status
849 | Rondanelli M, Klersy C, Perna S, et al. Effects of two-months balanced diet in metabolically healthy obesity: lipid correlations with gender and BMI-related differences. Lipids Health Dis. 2015;14:139. doi:10.1186/s12944-015-0131-1 | X | | X
850 | Ros E, Hu FB. Consumption of plant seeds and cardiovascular health: Epidemiological and clinical trial evidence. Circulation. 2013;128(5):553-565. doi:10.1161/circulationaha.112.001119 | X
851 | Rosado JL, Garcia OP, Ronquillo D, et al. Intake of milk with added micronutrients increases the effectiveness of an energy-restricted diet to reduce body weight: a randomized controlled clinical trial in Mexican women. J Am Diet Assoc. 2011;111(10):1507-16. doi:10.1016/j.jada.2011.07.011 | | X
852 | Rosenbaum M, Hall KD, Guo J, et al. Glucose and lipid homeostasis and inflammation in humans following an isocaloric ketogenic diet. Obesity (Silver Spring). 2019;27(6):971-981. doi:10.1002/oby.22468 | X | X
853 | Rosqvist F, Smedman A, Lindmark-Mansson H, et al. Potential role of milk fat globule membrane in modulating plasma lipoproteins, gene expression, and cholesterol metabolism in humans: a randomized study. Am J Clin Nutr. 2015;102(1):20-30. doi:10.3945/ajcn.115.107045 | | X
854 | Rousseaux J, Duhamel A, Dumont J, et al. The n-3 long-chain PUFAs modulate the impact of the GCKR Pro446Leu polymorphism on triglycerides in adolescents. J Lipid Res. 2015;56(9):1774-80. doi:10.1194/jlr.M057570 | X
855 | Roussell MA, Hill AM, Gaugler TL, et al. Beef in an optimal lean diet study: effects on lipids, lipoproteins, and apolipoproteins. Am J Clin Nutr. 2012;95(1):9-16. doi:10.3945/ajcn.111.016261 | | | | Health Status
856 | Roussell MA, Hill AM, Gaugler TL, et al. Effects of a DASH-like diet containing lean beef on vascular health. J Hum Hypertens. 2014;28(10):600-5. doi:10.1038/jhh.2014.34 | | X
857 | Roy SJ, Fico BG, Baker BD, et al. Effects of full-fat dairy products on subclinical vascular function in adults with elevated blood pressure: a randomized clinical trial. Eur J Clin Nutr. 2019;74(1):9-16. doi:10.1038/s41430-019-0435-8 | | X
858 | Roy SJ, Lapierre SS, Baker BD, Delfausse LA, Machin DR, Tanaka H. High dietary intake of whole milk and full-fat dairy products does not exert hypotensive effects in adults with elevated blood pressure. Nutr Res. 2019;6472-81. doi:10.1016/j.nutres.2019.01.003 | | X | | Health Status
859 | Ruel G, Shi Z, Zhen S, Zuo H, et al. Association between nutrition and the evolution of multimorbidity: the importance of fruits and vegetables and whole grain products. Clin Nutr. 2014;33(3):513-20. doi:10.1016/j.clnu.2013.07.009 | | X | | Country
860 | Ruisinger JF, Gibson CA, Backes JM, et al. Statins and almonds to lower lipoproteins (the STALL Study). J Clin Lipidol. 2015;9(1):58-64. doi:10.1016/j.jacl.2014.10.001 | | X | | Health Status
861 | Ruixing Y, Qiming F, Dezhai Y, et al. Comparison of demography, diet, lifestyle, and serum lipid levels between the Guangxi Bai Ku Yao and Han populations. J Lipid Res. 2007. 48(12):2673-2681. doi:10.1194/jlr.M700335-JLR200 | | X | | Country
862 | Ruiz N, Segarra AB, Lara L, Ramirez-Sanchez M, Prieto I. Diet and oxidative status. The dietary pattern and urinary 8-isoprostane in healthy Spanish women. Antioxidants (Basel). 2019;8(8): pii: E271. doi:10.3390/antiox8080271 | | | X
863 | Ruiz-Nunez B, Kuipers RS, Luxwolda MF, et al. Saturated fatty acid (SFA) status and SFA intake exhibit different relations with serum total cholesterol and lipoprotein cholesterol: a mechanistic explanation centered around lifestyle-induced low-grade inflammation. J Nutr Biochem. 2014;25(3):304-12. doi:10.1016/j.jnutbio.2013.11.004 | X | | | Country
864 | Ruscica M, Pavanello C, Gandini S, et al. Effect of soy on metabolic syndrome and cardiovascular risk factors: a randomized controlled trial. Eur J Nutr. 2018;57(2):499-511. doi:10.1007/s00394-016-1333-7 | | X
865 | Ryberg M, Sandberg S, Mellberg C, et al. A Palaeolithic-type diet causes strong tissue-specific effects on ectopic fat deposition in obese postmenopausal women. J Intern Med. 2013;274(1):67-76. doi:10.1111/joim.12048 | X | X
866 | Saarinen HJ, Sittiwet C, Simonen P, et al. Determining the mechanisms of dietary turnip rapeseed oil on cholesterol metabolism in men with metabolic syndrome. J Investig Med. 2018;66(1):11-16. doi:10.1136/jim-2017-000495 | | | X | Duplicate data
867 | Sabour H, Norouzi-Javidan A, Soltani Z, et al. The correlation between dietary fat intake and blood pressure among people with spinal cord injury. Iran J Neurol. 2016;15(3):121-7. | X | | | Health Status
868 | Saedi S, Noroozi M, Khosrotabar N, Mazandarani S, Ghadrdoost B. How canola and sunflower oils affect lipid profile and anthropometric parameters of participants with dyslipidemia. Med J Islam Repub Iran. 2017;315:5. doi:10.18869/mjiri.31.5 | | | | Health Status
869 | Sagawa N, Olson NC, Ahuja V, et al. Long chain n-3 polyunsaturated fatty acids are not associated with circulating T-helper type 1 cells: results from the Multi-Ethnic Study of Atherosclerosis (MESA). Prostaglandins Leukot Essent Fatty Acids. 2017;12537-42. doi:10.1016/j.plefa.2017.08.012 | | | X
870 | Saha S, Mundle M, Ghosh S, Koley M. Effects of medical nutrition therapy on plasma lipoproteins of type II dyslipidemic patients: a short-term pilot study. Asian Journal of Pharmaceutical and Clinical Research. 2012;5(Suppl 4):207-211. | | X | | Country
871 | Sala-Vila A, Romero-Mamani ES, Gilabert R, et al. Changes in ultrasound-assessed carotid intima-media thickness and plaque with a Mediterranean diet: a substudy of the PREDIMED trial. Arterioscler Thromb Vasc Biol. 2014;34(2):439-45. doi:10.1161/atvbaha.113.302327 | | X | X
872 | Sala-Vila A, Ros E. Mounting evidence that increased consumption of α-linolenic acid, the vegetable n-3 fatty acid, may benefit cardiovascular health. Clin Lipidol. 2011;6(4):365-369. doi:10.2217/clp.11.36 | X
873 | Salo P, Viikari J, Rask-Nissila L, et al. Effect of low-saturated fat, low-cholesterol dietary intervention on fatty acid compositions in serum lipid fractions in 5-year-old children. The STRIP project. Eur J Clin Nutr. 1999. 53(12):927-32. | | | | Duplicate data
874 | Samieri C, Lorrain S, Buaud B, et al. Relationship between diet and plasma long-chain n-3 PUFAs in older people: impact of apolipoprotein E genotype. J Lipid Res. 2013;54(9):2559-67. doi:10.1194/jlr.P036475 | X
875 | Samuelson G, Bratteby LE, Mohsen R, Vessby B. Dietary fat intake in healthy adolescents: inverse relationships between the estimated intake of saturated fatty acids and serum cholesterol. Br J Nutr. 2001. 85(3):333-41. doi:10.1079/bjn2000279 | X
876 | Sanchez-Rodriguez E, Biel-Glesson S, Fernandez-Navarro JR, et al. Effects of virgin olive oils differing in their bioactive compound contents on biomarkers of oxidative stress and inflammation in healthy adults: a randomized double-blind controlled trial. Nutrients. 2019;11(3): pii: E561. doi:10.3390/nu11030561 | | X | X
877 | Sanchez-Rodriguez E, Lima-Cabello E, Biel-Glesson S, et al. Effects of virgin olive oils differing in their bioactive compound contents on metabolic syndrome and endothelial functional risk biomarkers in healthy adults: a randomized double-blind controlled trial. Nutrients. 2018. 10(5): pii: E626. doi:10.3390/nu10050626 | | X
878 | Sanders TA, Lewis FJ, Goff LM, Chowienczyk PJ. SFAs do not impair endothelial function and arterial stiffness. Am J Clin Nutr. 2013;98(3):677-83. doi:10.3945/ajcn.113.063644 | | | X
879 | Saneei P, Hashemipour M, Kelishadi R, Rajaei S, Esmaillzadeh A. Effects of recommendations to follow the Dietary Approaches to Stop Hypertension (DASH) diet v. usual dietary advice on childhood metabolic syndrome: a randomised cross-over clinical trial. Br J Nutr. 2013;110(12):2250-9. doi:10.1017/s0007114513001724 | | X
880 | Santaren ID, Bazinet RP, Liu Z, et al. The distribution of fatty acid biomarkers of dairy intake across serum lipid fractions: the prospective metabolism and islet cell evaluation (PROMISE) Cohort. Lipids. 2019;54(10):617-627. doi:10.1002/lipd.12185 | X | X
881 | Sayer RD, Wright AJ, Chen N, Campbell WW. Dietary Approaches to Stop Hypertension diet retains effectiveness to reduce blood pressure when lean pork is substituted for chicken and fish as the predominant source of protein. Am J Clin Nutr. 2015;102(2):302-8. doi:10.3945/ajcn.115.111757 | | X
882 | Sayon-Orea C, Razquin C, Bullo M, et al. Effect of a nutritional and behavioral intervention on energy-reduced Mediterranean diet adherence among patients with metabolic syndrome: interim analysis of the PREDIMED-Plus randomized clinical trial. JAMA. 2019;322(15):1486-1499. doi:10.1001/jama.2019.14630 | | X
883 | Schaefer EJ, Tani M. Nutrition and coronary heart disease prevention. In Gang, A, eds. Dyslipidemias: Pathophysiology, Evaluation and Management. 2015:329-341. doi:10.1007/978-1-60761-424-1_19 | X | | | Publication Status
884 | Schlienger JL, Paillard F, Lecerf JM, et al. Effect on blood lipids of two daily servings of Camembert cheese. An intervention trial in mildly hypercholesterolemic subjects. Int J Food Sci Nutr. 2014;65(8):1013-8. doi:10.3109/09637486.2014.945156 | | | | Health Status
885 | Schreuder YJ, Hutten BA, van Eijsden M, et al. Ethnic differences in maternal total cholesterol and triglyceride levels during pregnancy: the contribution of demographics, behavioural factors and clinical characteristics. Eur J Clin Nutr. 2011;65(5):580-9. doi:10.1038/ejcn.2010.282 | X | X
886 | Schroder H, Salas-Salvado J, Martinez-Gonzalez MA, et al. Baseline adherence to the Mediterranean diet and major cardiovascular events: Prevencion con Dieta Mediterranea trial. JAMA Intern Med. 2014;174(10):1690-2. doi:10.1001/jamainternmed.2014.3463 | | X
887 | Schuler R, Osterhoff MA, Frahnow T, et al. High-saturated-fat diet increases circulating angiotensin-converting enzyme, which is enhanced by the rs4343 polymorphism defining persons at risk of nutrient-dependent increases of blood pressure. J Am Heart Assoc. 2017;6(1):p ii: e004465. doi:10.1161/jaha.116.004465 | | X | X
888 | Schumacher TL, Burrows TL, Rollo ME, Wood LG, Callister R, Collins CE. Comparison of fatty acid intakes assessed by a cardiovascular-specific food frequency questionnaire with red blood cell membrane fatty acids in hyperlipidaemic Australian adults: a validation study. Eur J Clin Nutr. 2016. 70(12):1433-1438. doi:10.1038/ejcn.2016.144 | X | | X
889 | Schwab US, Lankinen MA, de Mello VD, et al. Camelina sativa oil, but not fatty fish or lean fish, improves serum lipid profile in subjects with impaired glucose metabolism-a randomized controlled trial. Mol Nutr Food Res. 2018;62(4). doi:10.1002/mnfr.201700503 | | | | Product not widely available in the US
890 | Schwandt P, Bertsch T, Haas GM. Sustained lifestyle advice and cardiovascular risk factors in 687 biological child-parent pairs: the PEP Family Heart Study. Atherosclerosis. 2011;219(2):937-45. doi:10.1016/j.atherosclerosis.2011.09.032 | | X
891 | Schwandt P, Haas GM, Bertsch T. Nutrition and cardiovascular risk factors in four age groups of female individuals: The PEP family heart study. International Journal of Preventive Medicine. 2010;1(2):103-109. | X
892 | Schwandt P, Haas GM, Liepold E. Lifestyle and cardiovascular risk factors in 2001 child-parent pairs: the PEP Family Heart Study. Atherosclerosis. 2010;213(2):642-8. doi:10.1016/j.atherosclerosis.2010.09.032 | X | X
893 | Sciarrillo CM, Koemel NA, Tomko PM, Bode KB, Emerson SR. Postprandial lipemic responses to various sources of saturated and monounsaturated fat in adults. Nutrients. 2019;11(5): pii: E1089. doi:10.3390/nu11051089 | X | | X
894 | Seah JY, Ong CN, Koh WP, Yuan JM, van Dam RM. A dietary pattern derived from reduced rank regression and fatty acid biomarkers is associated with lower risk of type 2 diabetes and coronary artery disease in Chinese adults. J Nutr. 2019;149(11):2001-2010. doi:10.1093/jn/nxz164 | | X
895 | Seidel C, Deufel T, Jahreis G. Effects of fat-modified dairy products on blood lipids in humans in comparison with other fats. Ann Nutr Metab. 2005. 49(1):42-8. doi:10.1159/000084176 | | | | Study Duration
896 | Seki K, Hasuike-Seo M, Kondo S, Sato N, Suzuki E, Hasumi K. Effects of intake of sesame oil (kadoya pure sesame oil) on the level of serum cholesterol in volunteers with slightly higher serum cholesterol - A randomized, double-blind, parallel-group, placebo-controlled study. Japanese Pharmacology and Therapeutics. 2015;43(5):687-696. | | | | Health Status
897 | Seki K, Ishikawa T, Hasuike-Seo M, Suzuki E, Kondo S, Hasumi K. Hypocholesterolemic effect of sesame oil (Kadoya Pure Sesame Oil) - A verification test with a randomized, double-blind, parallel-group, placebo-controlled study. Japanese Pharmacology and Therapeutics. 2015;43(10):1473-1480. | | | | Health Status
898 | Sellem L, Srour B, Gueraud F, et al. Saturated, mono- and polyunsaturated fatty acid intake and cancer risk: results from the French prospective cohort NutriNet-Sante. Eur J Nutr. 2019;58(4):1515-1527. doi:10.1007/s00394-018-1682-5 | | | X
899 | Setayeshgar S, Ekwaru JP, Maximova K, et al. Dietary intake and prospective changes in cardiometabolic risk factors in children and youth. Appl Physiol Nutr Metab. 2017;42(1):39-45. doi:10.1139/apnm-2016-0215 | | X
900 | Severins N, Mensink RP, Plat J. Effects of lutein-enriched egg yolk in buttermilk or skimmed milk on serum lipids & lipoproteins of mildly hypercholesterolemic subjects. Nutr Metab Cardiovasc Dis. 2015;25(2):210-7. doi:10.1016/j.numecd.2014.10.003 | | X
901 | Shah BS, Freeland-Graves JH, Cahill JM, Lu H, Graves GR. Diet quality as measured by the healthy eating index and the association with lipid profile in low-income women in early postpartum. J Am Diet Assoc. 2010;110(2):274-9. doi:10.1016/j.jada.2009.10.038 | X | X
902 | Shah M, Adams-Huet B, Franklin B, Phillips M, Mitchell J. The effects of high-protein and high-monounsaturated fat meals on postprandial lipids, lipoprotein particle numbers, cytokines, and leptin responses in overweight/obese subjects. Metab Syndr Relat Disord. 2018;16(3):150-158. doi:10.1089/met.2017.0167 | X | | X
903 | Shang X, Sanders KM, Scott D, et al. Dietary alpha-linolenic acid and total omega-3 fatty acids are inversely associated with abdominal aortic calcification in older women but not in older men. J Nutr. 2015;145(8):1778-86. doi:10.3945/jn.115.211789 | | | X
904 | Shannon BM, Tershakovec AM, Martel JK, et al. Reduction of elevated LDL-cholesterol levels of 4- to 10-year-old children through home-based dietary education. Pediatrics. 1994. 94(6 Pt 1):923-7. | | X
905 | Shatwan IM, Weech M, Jackson KG, Lovegrove JA, Vimaleswaran KS. Apolipoprotein E gene polymorphism modifies fasting total cholesterol concentrations in response to replacement of dietary saturated with monounsaturated fatty acids in adults at moderate cardiovascular disease risk. Lipids Health Dis. 2017;16(1):222. doi:10.1186/s12944-017-0606-3 | | X
906 | Shay CM, Stamler J, Dyer AR, et al. Nutrient and food intakes of middle-aged adults at low risk of cardiovascular disease: the international study of macro-/micronutrients and blood pressure (INTERMAP). Eur J Nutr. 2012;51(8):917-26. doi:10.1007/s00394-011-0268-2 | X
907 | Shea S, Basch CE, Irigoyen M, Zybert P, Contento I, Gutin B. Relationships between diet and blood lipid levels in Hispanic preschool children. Ann N Y Acad Sci. 1991. 623:462-3. doi:10.1111/j.1749-6632.1991.tb43772.x | X
908 | Shea S, Basch CE, Irigoyen M, et al. Relationships of dietary fat consumption to serum total and low-density lipoprotein cholesterol in hispanic preschool children. Prev Med. 1991. 20(2):237-49. doi:10.1016/0091-7435(91)90023-w | X
909 | Shi Z, Riley M, Brown A, Page A. Chilli intake is inversely associated with hypertension among adults. Clin Nutr ESPEN. 2018;2367-72. doi:10.1016/j.clnesp.2017.12.007 | X | X
910 | Shih CW, Hauser ME, Aronica L, Rigdon J, Gardner CD. Changes in blood lipid concentrations associated with changes in intake of dietary saturated fat in the context of a healthy low-carbohydrate weight-loss diet: a secondary analysis of the Diet Intervention Examining The Factors Interacting with Treatment Success (DIETFITS) trial. Am J Clin Nutr. 2019;109(2):433-441. doi:10.1093/ajcn/nqy305 | X | | X
911 | Shiue I, Arima H, Hankey GJ, Anderson CS. Dietary intake of key nutrients and subarachnoid hemorrhage: a population-based case-control study in Australasia. Cerebrovasc Dis. 2011;31(5):464-70. doi:10.1159/000324386 | X | X
912 | Shojasaadat F, Ayremlou P, Hashemi A, Mehdizadeh A, Zarrin R. A randomized controlled trial comparing effects of a low-energy diet with n-3 polyunsaturated fatty acid supplementation in patients with non-alcoholic fatty liver disease. J Res Med Sci. 2019;2421. doi:10.4103/jrms.JRMS_282_18 | | X | | Health Status
913 | Silva S, Bronze MR, Figueira ME, et al. Impact of a 6-wk olive oil supplementation in healthy adults on urinary proteomic biomarkers of coronary artery disease, chronic kidney disease, and diabetes (types 1 and 2): a randomized, parallel, controlled, double-blind study. Am J Clin Nutr. 2015;101(1):44-54. doi:10.3945/ajcn.114.094219 | | X
914 | Silva S, Bronze MR, Figueira ME, et al. Impact of a six-week olive oil supplementation in healthy adults on urinary proteomic biomarkers of coronary artery disease, chronic kidney disease and diabetes. Atherosclerosis. 2015;241(1):e41. doi:10.1016/j.atherosclerosis.2015.04.146 | | | | Publication Status
915 | Silva VM, Vinagre CGC, Dallan LAO, Chacra APM, Maranhão RC. Plasma lipids, lipoprotein metabolism and HDL lipid transfers are equally altered in metabolic syndrome and in type 2 diabetes. Lipids. 2014;49(7):677-684. doi:10.1007/s11745-014-3899-2 | | X
916 | Silver HJ, Kang H, Keil CD, et al. Consuming a balanced high fat diet for 16 weeks improves body composition, inflammation and vascular function parameters in obese premenopausal women. Metabolism. 2014;63(4):562-73. doi:10.1016/j.metabol.2014.01.004 | | X
917 | Silver HJ, Niswender KD, Keil CD, et al. CNR1 genotype influences HDL-cholesterol response to change in dietary fat intake. PLoS One. 2012;7(5):e36166. doi:10.1371/journal.pone.0036166 | | X
918 | Simell O, Niinikoski H, Viikari J, Rask-Nissila L, Tammi A, Ronnemaa T. Cardiovascular disease risk factors in young children in the STRIP baby project. Special Turku coronary risk factor intervention project for children. Ann Med. 1999. 31 Suppl 155-61. | | | | Duplicate data
919 | Simon JA, Morrison JA, Similo SL, McMahon RP, Schreiber GB. Correlates of high-density lipoprotein cholesterol in Black girls and White girls: the NHLBI Growth and Health Study. Am J Public Health. 1995. 85(12):1698-702. doi:10.2105/ajph.85.12.1698 | X
920 | Simprini LA, Villines TC, Rich M, Taylor AJ. The relationship between subclinical atherosclerosis, non-high-density lipoprotein cholesterol, exercise, and diet among male participants of the PACC Project. J Clin Lipidol. 2012;6(2):174-9. doi:10.1016/j.jacl.2011.11.005 | X | X
921 | Skilton MR, Mikkila V, Wurtz P, et al. Fetal growthomega-3 (n-3) fatty acids, and progression of subclinical atherosclerosis: preventing fetal origins of disease? The Cardiovascular Risk in Young Finns Study. Am J Clin Nutr. 2013;97(1):58-65. doi:10.3945/ajcn.112.044198 | | | X | Health Status
922 | Skorkowska-Telichowska K, Kosinska J, Chwojnicka M, et al. Positive effects of egg-derived phospholipids in patients with metabolic syndrome. Adv Med Sci. 2016;61(1):169-74. doi:10.1016/j.advms.2015.12.003 | | X
923 | Skouroliakou M, Grosomanidis D, Massara P, Kostara C, et al. Serum antioxidant capacity, biochemical profile and body composition of breast cancer survivors in a randomized Mediterranean dietary intervention study. Eur J Nutr. 2018;57(6):2133-2145. doi:10.1007/s00394-017-1489-9 | | X | | Health Status
924 | Skuladottir M, Ramel A, Rytter D, et al. Examining confounding by diet in the association between perfluoroalkyl acids and serum cholesterol in pregnancy. Environ Res. 2015;143(Pt A):33-8. doi:10.1016/j.envres.2015.09.001 | X | X
925 | Slade AN, Kim H. Dietary responses to a hypertension diagnosis: evidence from the National Health and Nutrition Examination Survey (NHANES) 2007-2010. Behav Med. 2014;40(1):1-13. doi:10.1080/08964289.2013.826171 | X
926 | Sluijs I, Praagman J, Boer JMA, Verschuren WMM, van der Schouw YT. Fluidity of the dietary fatty acid profile and risk of coronary heart disease and ischemic stroke: results from the EPIC-Netherlands cohort study. Nutr Metab Cardiovasc Dis. 2017;27(9):799-805. doi:10.1016/j.numecd.2017.06.008 | X | X
927 | Smidowicz A, Regula J. Dietary gender differences in terms of the risk of atherogenesis in Poland. Acta Sci Pol Technol Aliment. 2015;14(3):257-267. doi:10.17306/j.Afs.2015.3.37 | X | X
928 | Smit LA, Baylin A, Campos H. Conjugated linoleic acid in adipose tissue and risk of myocardial infarction. Am J Clin Nutr. 2010;92(1):34-40. doi:10.3945/ajcn.2010.29524 | X
929 | Smith KM, Barraj LM, Kantor M, Sahyoun NR. Relationship between fish intake, n-3 fatty acids, mercury and risk markers of CHD (National Health and Nutrition Examination Survey 1999-2002). Public Health Nutr. 2009. 12(8):1261-9. doi:10.1017/s1368980008003844 | X
930 | Snetselaar L, Stumbo P, Chenard C, Ahrens L, Smith K, Zimmerman B. Adolescents eating diets rich in either lean beef or lean poultry and fish reduced fat and saturated fat intake and those eating beef maintained serum ferritin status. J Am Diet Assoc. 2004. 104(3):424-8. doi:10.1016/j.jada.2003.12.016 | | X | X
931 | Soedamah-Muthu SS, Masset G, Verberne L, Geleijnse JM, Brunner EJ. Consumption of dairy products and associations with incident diabetes, CHD and mortality in the Whitehall II study. Br J Nutr. 2013;109(4):718-26. doi:10.1017/s0007114512001845 | | X
932 | Soerensen KV, Thorning TK, Astrup A, Kristensen M, Lorenzen JK. Effect of dairy calcium from cheese and milk on fecal fat excretion, blood lipids, and appetite in young men. Am J Clin Nutr. 2014;99(5):984-91. doi:10.3945/ajcn.113.077735 | | X | | Study Duration
933 | Sola R, Fito M, Estruch R, Salas-Salvado J, et al. Effect of a traditional Mediterranean diet on apolipoproteins B, A-I, and their ratio: a randomized, controlled trial. Atherosclerosis. 2011;218(1):174-80. doi:10.1016/j.atherosclerosis.2011.04.026 | | X
934 | Sola R, Valls RM, Godas G, Perez-Busquets G, et al. Cocoa, hazelnuts, sterols and soluble fiber cream reduces lipids and inflammation biomarkers in hypertensive patients: a randomized controlled trial. PLoS One. 2012;7(2):e31103. doi:10.1371/journal.pone.0031103 | | X
935 | Somerset S, Graham L, Markwell K, Colquhoun D. Isoenergetic replacement of dietary saturated with monounsaturated fat via macadamia nuts can affect coronary risk in overweight subjects. Atherosclerosis supplements. 2011;12(1):143- 144. doi: 10.1016/S1567-5688(11)70684-5 | | | | Publication Status
936 | Somerset SM, Graham L, Markwell K. Isoenergetic replacement of dietary saturated with monounsaturated fat via macadamia nuts enhances endothelial function in overweight subjects. Clin Nutr ESPEN. 2013;8(3):e113-e119. doi:10.1016/j.clnme.2013.02.003 | | X
937 | Sondike SB, Copperman N, Jacobson MS. Effects of a low-carbohydrate diet on weight loss and cardiovascular risk factor in overweight adolescents. J Pediatr. 2003. 142(3):253-8. doi:10.1067/mpd.2003.4 | | X
938 | Sonestedt E, Gullberg B, Ericson U, Wirfalt E, Hedblad B, Orho-Melander M. Association between fat intake, physical activity and mortality depending on genetic variation in FTO. Int J Obes (Lond). 2011;35(8):1041-9. doi:10.1038/ijo.2010.263 | | X
939 | Sonestedt E, Hellstrand S, Drake I, et al. Diet quality and change in blood lipids during 16 years of follow-up and their interaction with genetic risk for dyslipidemia. Nutrients. 2016;8(5): pii: E274. doi:10.3390/nu8050274 | | | X
940 | Song J, Jiang X, Cao Y, Juan J, Wu T, Hu Y. Interaction between an ATP-binding cassette A1 (ABCA1) variant and egg consumption for the risk of ischemic stroke and carotid atherosclerosis: a family-based study in the Chinese population. J Atheroscler Thromb. 2019;26(9):835-845. doi:10.5551/jat.46615 | | X
941 | Song S, Paik HY, Park M, Song Y. Dyslipidemia patterns are differentially associated with dietary factors. Clin Nutr. 2016;35(4):885-91. doi:10.1016/j.clnu.2015.06.002 | X
942 | Song X, Huang Y, Neuhouser ML, et al. Dietary long-chain fatty acids and carbohydrate biomarker evaluation in a controlled feeding study in participants from the Women’s Health Initiative cohort. Am J Clin Nutr. 2017;105(6):1272-1282. doi:10.3945/ajcn.117.153072 | | | X
943 | Srour B, Fezeu LK, Kesse-Guyot E, et al. Ultra-processed food intake and risk of cardiovascular disease: prospective cohort study (NutriNet-Sante). BMJ. 2019;365:l1451. doi:10.1136/bmj.l1451 | | X
944 | Stelmach-Mardas M, Walkowiak J, Wieckowska B, Przyslawski J. Polyunsaturated fatty acids and not plant sterols naturally-occurring in food influence lipid profile in obese women. Acta Sci Pol Technol Aliment. 2014;13(1):111-7. | X | | | Health Status
945 | Stevenson JL, Miller MK, Skillman HE, Paton CM, Cooper JA. A PUFA-rich diet improves fat oxidation following saturated fat-rich meal. Eur J Nutr. 2017;56(5):1845-1857. doi:10.1007/s00394-016-1226-9 | | | | Study Duration
946 | Stocks T, Taylor MA, Angquist L, et al. Change in proportional protein intake in a 10-week energy-restricted low- or high-fat diet, in relation to changes in body size and metabolic factors. Obes Facts. 2013;6(3):217-27. doi:10.1159/000351726 | | X
947 | Storniolo CE, Casillas R, Bullo M, et al. A Mediterranean diet supplemented with extra virgin olive oil or nuts improves endothelial markers involved in blood pressure control in hypertensive women. Eur J Nutr. 2017;56(1):89-97. doi:10.1007/s00394-015-1060-5 | | X | | Health Status
948 | Streppel MT, Sluik D, van Yperen JF, et al. Nutrient-rich foodscardiovascular diseases and all-cause mortality: the Rotterdam study. Eur J Clin Nutr. 2014;68(6):741-7. doi:10.1038/ejcn.2014.35 | | X
949 | Strom M, Mortensen EL, Henriksen TB, Olsen SF. Fish consumption measured during pregnancy and risk of cardiovascular diseases later in life: an observational prospective study. PLoS One. 2011;6(11):e27330. doi:10.1371/journal.pone.0027330 | | X
950 | Stulnig TM, Leitner L, Marculescu R, Zeyda M, Itariu BK. Does treatment with n-3 polyunsaturated fatty acids influence vitamin D status in severely obese non-diabetic subjects?. Diabetologia. 2012;55:S363- . doi:10.1007/s00125-012-2688-9 | | | | Publication Status
951 | Stupin A, Rasic L, Matic A, et al. Omega-3 polyunsaturated fatty acids-enriched hen eggs consumption enhances microvascular reactivity in young healthy individuals. Appl Physiol Nutr Metab. 2018;43(10):988-995. doi:10.1139/apnm-2017-0735 | | | X | Study Duration
952 | Sundfor TM, Svendsen M, Heggen E, Dushanov S, Klemsdal TO, Tonstad S. BMI modifies the effect of dietary fat on atherogenic lipids: a randomized clinical trial. Am J Clin Nutr. 2019;110(4):832-841. doi:10.1093/ajcn/nqz113 | | | | Health Status
953 | Sureda A, Bibiloni MD, Martorell M, et al. Mediterranean diets supplemented with virgin olive oil and nuts enhance plasmatic antioxidant capabilities and decrease xanthine oxidase activity in people with metabolic syndrome: The PREDIMED study. Mol Nutr Food Res. 2016;60(12):2654-2664. doi:10.1002/mnfr.201600450 | | X | X
954 | Suter E, Hawes MR. Relationship of physical activity, body fat, diet, and blood lipid profile in youths 10-15 yr. Med Sci Sports Exerc. 1993. 25(6):748-54. | X | X
955 | Svendsen K, Henriksen HB, Ostengen B, et al. Evaluation of a short Food Frequency Questionnaire to assess cardiovascular disease-related diet and lifestyle factors. Food Nutr Res. 2018;19:62. doi:10.29219/fnr.v62.1370 | | | X
956 | Szymlek-Gay EA, Gray AR, Heath AM, Ferguson EL, Skeaff CM. Red meat consumption and serum lipids and fatty acids in toddlers: secondary outcomes of a randomized controlled trial. J Pediatr Gastroenterol Nutr. 2018;67(3):395-400. doi:10.1097/mpg.0000000000002018 | | X
957 | Taba N, Fischer K, Esko T, Metspalu A, Pirastu N. Investigating causal relationships between dietary items and blood metabolites using 2-sample mendelian randomization. Human Heredity. 2017;83(5):244- 245. doi:10.1159/000499459 | | | | Publication Status
958 | Tagetti A, Ericson U, Montagnana M, et al. Intakes of omega-3 polyunsaturated fatty acids and blood pressure change over time: possible interaction with genes involved in 20-HETE and EETs metabolism. Prostaglandins Other Lipid Mediat. 2015;120:126-33. doi:10.1016/j.prostaglandins.2015.05.003 | | | X
959 | Taguchi C, Kishimoto Y, Suzuki-Sugihara N, et al. Regular egg consumption at breakfast by Japanese woman university students improves daily nutrient intakes: open-labeled observations. Asia Pac J Clin Nutr. 2018;27(2):359-365. doi:10.6133/apjcn.042017.17 | X | X
960 | Tahir FN, Danyal M, Shah SIA, Qureshi JA. Lipid lowering effect of almonds (Prunus dulcis) in healthy adults. Pakistan Journal of Medical and Health Sciences. 2018;12(4):1356-1358. | | | | Country
961 | Taing CY, Gibson AA, Colagiuri S, et al. Primary analysis of the Mandarin-speaking sub-study within the Sydney diabetes prevention program. Diabetes Res Clin Pract. 2017;132:118-126. doi:10.1016/j.diabres.2017.07.032 | | X
962 | Takagi H, Kobayashi Y, Taguchi O, Takei Y, Sumida Y. Influence of dietary intake of fish oil, magnesium, and zinc on metabolic parameters among individuals tested for diabetes. Nutrition. 2015;31(7-8):988-93. doi:10.1016/j.nut.2015.02.019 | X
963 | Takata Y, Zhang X, Li H, et al. Fish intake and risks of total and cause-specific mortality in 2 population-based cohort studies of 134,296 men and women. Am J Epidemiol. 2013;178(1):46-57. doi:10.1093/aje/kws584 | | | | Country
964 | Tammi A, Ronnemaa T, Gylling H, et al. Plant stanol ester margarine lowers serum total and low-density lipoprotein cholesterol concentrations of healthy children: the STRIP project. Special Turku Coronary Risk Factors Intervention Project. J Pediatr. 2000. 136(4):503-10. doi:10.1016/s0022-3476(00)90014-3 | | X
965 | Tammi A, Ronnemaa T, Miettinen TA, et al. Effects of gender, apolipoprotein E phenotype and cholesterol-lowering by plant stanol esters in children: the STRIP study. Special Turku Coronary Risk Factor Intervention Project. Acta Paediatr. 2002;91(11):1155-62. doi:10.1080/080352502320777379 | | X
966 | Tang H, Zhang Z, Li Z, Lin J, Fang DZ. High-carbohydrate/low-fat diet-induced gender-specific serum lipid profile changes are associated with LEPR polymorphisms in Chinese youth. Ann Nutr Metab. 2017;70(1):1-8. doi:10.1159/000455165 | | X
967 | Tani S, Matsuo R, Matsumoto N. A longitudinal study of the association of the eicosapentaenoic acid/arachidonic acid ratio derived from fish consumption with the serum lipid levels: a pilot study. Heart Vessels. 2019;34(1):189-196. doi:10.1007/s00380-018-1226-1 | | X
968 | Taylor C, Perera D, Wilson A, Zahradka P. Arterial stiffness interferes with LDL-cholesterol lowering by canola oil in persons with mild hypercholesterolemia. FASEB journal. 2017;31(1):. | | | | Publication Status
969 | Tayyem RF, Al-Shudifat AE, Johannessen A, et al. Dietary patterns and the risk of coronary heart disease among Jordanians: a case-control study. Nutr Metab Cardiovasc Dis. 2018;28(3):262-269. doi:10.1016/j.numecd.2017.10.026 | | X
970 | Te Morenga LA, Levers MT, Williams SM, Brown RC, Mann J. Comparison of high protein and high fiber weight-loss diets in women with risk factors for the metabolic syndrome: a randomized trial. Nutr J. 2011. 10:40. doi:10.1186/1475-2891-10-40 | | X
971 | te Velde SJ, Snijder MB, van Dijk AE, et al. Dairy intake from adolescence into adulthood is not associated with being overweight and metabolic syndrome in adulthood: the Amsterdam Growth and Health Longitudinal Study. J Hum Nutr Diet. 2011. 24(3):233-244. doi:10.1111/j.1365-277X.2010.01149.x | | X
972 | Tektonidis TG, Akesson A, Gigante B, Wolk A, Larsson SC. A Mediterranean diet and risk of myocardial infarctionheart failure and stroke: a population-based cohort study. Atherosclerosis. 2015;243(1):93-8. doi:10.1016/j.atherosclerosis.2015.08.039 | | X
973 | Telford RD, Cunningham RB, Waring P, et al. Sensitivity of blood lipids to changes in adiposity, exercise, and diet in children. Med Sci Sports Exerc. 2015;47(5):974-82. doi:10.1249/mss.0000000000000493 | | X
974 | Telle-Hansen VH, Larsen LN, Hostmark AT, et al. Daily intake of cod or salmon for 2 weeks decreases the 18:1n-9/18:0 ratio and serum triacylglycerols in healthy subjects. Lipids. 2012;47(2):151-60. doi:10.1007/s11745-011-3637-y | | X
975 | Telle-Hansen VH, Narverud I, Retterstol K, et al. Substitution of TAG oil with diacylglycerol oil in food items improves the predicted 10 years cardiovascular risk score in healthy, overweight subjects. J Nutr Sci. 2012;1. doi:10.1017/jns.2012.18 | | X
976 | Tennakoon SU, Kumar BN, Meyer HE. Differences in selected lifestyle risk factors for cardiovascular disease between Sri Lankans in Oslo, Norway, and in Kandy, Sri Lanka. Asia Pac J Public Health. 2015. 27(2):Np616-25. doi:10.1177/1010539513485973 | X | | X
977 | Teymoori F, Asghari G, Salehi P, Sadeghian S, Mirmiran P, Azizi F. Are dietary amino acids prospectively predicts changes in serum lipid profile?. Diabetes Metab Syndr. 2019. 13(3):1837-1843. doi:10.1016/j.dsx.2019.04.013 | | X
978 | Thiengwiboonwong S, Chongsuwat R, Temcharoen P, Pandii W, Pavadhgul P. Efficacy of dietary modification following the National Cholesterol Education Program (NCEP) recommendation on lipid profiles among hyperlipidemia subjects. J Med Assoc Thai. 2013;96(10):1257-67. | | | | Health Status
979 | Tholstrup T, Hjerpsted J, Raff M. Palm olein increases plasma cholesterol moderately compared with olive oil in healthy individuals. Am J Clin Nutr. 2011;94(6):1426-32. doi:10.3945/ajcn.111.018846 | | | | Study Duration
980 | Thomas J, Chan L, Wray A, et al. Does the presence of cardiovascular disease risk factors or established disease influence the dietary intake of affected adults and their children residing in the same household? A secondary analysis of the Australian Health Survey (2011-2013). BMC Cardiovasc Disord. 2017. 17(1):146. doi:10.1186/s12872-017-0578-2 | X | | X
981 | Thomson CA, Stopeck AT, Bea JW, et al. Changes in body weight and metabolic indexes in overweight breast cancer survivors enrolled in a randomized trial of low-fat vs. reduced carbohydrate diets. Nutr Cancer. 2010. 62(8):1142-52. doi:10.1080/01635581.2010.513803 | | X
982 | Thorning TK, Raziani F, Bendsen NT, Astrup A, Tholstrup T, Raben A. Diets with high-fat cheese, high-fat meat, or carbohydrate on cardiovascular risk markers in overweight postmenopausal women: a randomized crossover trial. Am J Clin Nutr. 2015;102(3):573-81. doi:10.3945/ajcn.115.109116 | | | | Study Duration
983 | Tierney AC, McMonagle J, Shaw DI, et al. Effects of dietary fat modification on insulin sensitivity and on other risk factors of the metabolic syndrome-LIPGENE: a European randomized dietary intervention study. Int J Obes. 2011. 35(6):800-809. doi:10.1038/ijo.2010.209 | | X
984 | Toledo E, Hu FB, Estruch R, et al. Effect of the Mediterranean diet on blood pressure in the PREDIMED trial: results from a randomized controlled trial. BMC Med. 2013. 11:207. doi:10.1186/1741-7015-11-207 | | X
985 | Toledo E, Wang DD, Ruiz-Canela M, et al. Plasma lipidomic profiles and cardiovascular events in a randomized intervention trial with the Mediterranean diet. Am J Clin Nutr. 2017;106(4):973-983. doi:10.3945/ajcn.116.151159 | | X
986 | Tomdio A, Ritchie M, Miller AC. Omega-3 fatty acids and cardiovascular disease prevention. Am Fam Physician. 2019. 100(4):209-210. | X
987 | Torres-Pena JD, Garcia-Rios A, Delgado-Casado N, et al. Mediterranean diet improves endothelial function in patients with diabetes and prediabetes: a report from the CORDIOPREV study. Atherosclerosis. 2018;269:50-56. doi:10.1016/j.atherosclerosis.2017.12.012 | | X | | Health Status
988 | Tørris C, Molin M, Cvancarova Småstuen M. Lean fish consumption is associated with beneficial changes in the metabolic syndrome components: a 13-year follow-up study from the Norwegian Tromsø Study. Nutrients. 2017;9(3). pii: E247 doi:10.3390/nu9030247 | | X
989 | Torvik K, Narverud I, Ottestad I, et al. Dietary counseling is associated with an improved lipid profile in children with familial hypercholesterolemia. Atherosclerosis. 2016;252:21-27. doi:10.1016/j.atherosclerosis.2016.07.913 | X | | | Health Status
990 | Tran N, Barraj L. Contribution of specific dietary factors to CHD in US females. Public Health Nutr. 2010. 13(2):154-62. doi:10.1017/s1368980009990693 | X
991 | Trico D, Trifiro S, Mengozzi A, et al. Reducing Cholesterol and Fat Intake Improves Glucose Tolerance by Enhancing beta Cell Function in Nondiabetic Subjects. J Clin Endocrinol Metab. 2018. 103(2):622-631. doi:10.1210/jc.2017-02089 | | X | X
992 | Tröbs M, Renner T, Scherer G, et al. Nutrition, antioxidants, and risk factor profile of nonsmokers, passive smokers and smokers of the Prevention Education Program (PEP) in Nuremberg, Germany. Prev Med. 2002. 34(6):600-607. doi:10.1006/pmed.2002.1024 | | X
993 | Trude AC, Kharmats A, Jock B, et al. Patterns of food consumption are associated with obesity, self-reported diabetes and cardiovascular disease in five American Indian communities. Ecol Food Nutr. 2015. 54(5):437-54. doi:10.1080/03670244.2014.922070 | X | X
994 | Tsaban G, Wolak A, Avni-Hassid H, et al. Dynamics of intrapericardial and extrapericardial fat tissues during long-term, dietary-induced, moderate weight loss. Am J Clin Nutr. 2017;106(4):984-995. doi:10.3945/ajcn.117.157115 | | X
995 | Tsugane S, Sawada N. The JPHC study: design and some findings on the typical Japanese diet. Jpn J Clin Oncol. 2014. 44(9):777-82. doi:10.1093/jjco/hyu096 | X
996 | Tura A, Conte B, Caparrotto C, et al. Insulin sensitivity and secretion in young, healthy subjects are not changed by Zone and Mediterranean diets. Med J Nutrition Metab. 2010. 3(3):233-237. doi:10.1007/s12349-010-0026-7 | | X
997 | Turcot V, Brunet J, Daneault C, Tardif JC, Des Rosiers C, Lettre G. Validation of fatty acid intakes estimated by a food frequency questionnaire using erythrocyte fatty acid profiling in the Montreal Heart Institute Biobank. J Hum Nutr Diet. 2015;28(6):646-58. doi:10.1111/jhn.12272 | | | X
998 | Turner KM, Keogh JB, Meikle PJ, Clifton PM. Changes in lipids and inflammatory markers after consuming diets high in red meat or dairy for four weeks. Nutrients. 2017;9(8): pii: E886. doi:10.3390/nu9080886 | | X
999 | Turunen AW, Jula A, Suominen AL, et al. Fish consumption, omega-3 fatty acids, and environmental contaminants in relation to low-grade inflammation and early atherosclerosis. Environ Res. 2013;12043-54. doi:10.1016/j.envres.2012.09.007 | X | X
1000 | Ugidos IF, Perez-Rodriguez D, Fernandez-Lopez A. A role for lipids as agents to alleviate stroke damage: the neuroprotective effect of 2-hydroxy arachidonic acid. Neural Regen Res. 2017. 12(8):1273-1275. doi:10.4103/1673-5374.213545 | X
1001 | Ulven SM, Christensen JJ, Nygard O, et al. Using metabolic profiling and gene expression analyses to explore molecular effects of replacing saturated fat with polyunsaturated fat-a randomized controlled dietary intervention study. Am J Clin Nutr. 2019;109(5):1239-1250. doi:10.1093/ajcn/nqy356 | | | | Health Status
1002 | Ulven SM, Leder L, Elind E, et al. Exchanging key food items in daily diet improves fat quality and reduces total cholesterol and LDL cholesterol-a randomized controlled trial. Ann Nut Metab. 2015. 67(Suppl 1):370- 371. doi:10.1159/000440895 | | | | Publication Status
1003 | Ulven SM, Leder L, Elind E, et al. Replacing dietary saturated fat with polyunsaturated fat reduces total cholesterol and LDL cholesterol in healthy subjects with moderate hypercholesterolaemia-a randomized controlled trial. Atherosclerosis. 2015. 241(1): E194-E194. doi: 10.1016/j.atherosclerosis.2015.04.946 | | | | Publication Status
1004 | Ulven SM, Leder L, Elind E, et al. Exchanging a few commercial regularly consumed food items with improved fat quality reduces total cholesterol and LDL-cholesterol: A double-blind randomised controlled trial. Br J Nutr. 2016;116(8):1383-1393. doi:10.1017/s0007114516003445 | | | | Health Status
1005 | Um CY, Judd SE, Flanders WD, Fedirko V, Bostick RM. Associations of calcium and dairy products with all-cause and cause-specific mortality in the REasons for Geographic and Racial Differences in Stroke (REGARDS) Prospective Cohort Study. Nutr Cancer. 2017;69(8):1185-1195. doi:10.1080/01635581.2017.1367946 | | X
1006 | Um CY, Prizment A, Hong CP, Lazovich D, Bostick RM. Associations of calcium and dairy product intakes with all-cause, all-cancer, colorectal cancer and coronary heart disease mortality among older women in the Iowa Women’s Health Study. Br J Nutr. 2019. 121(10):1188-1200. doi:10.1017/S000711451900045X | | X
1007 | Um YJ, Oh SW, Lee CM, et al. Dietary fat intake and the risk of metabolic syndrome in Korean Adults. Korean J Fam Med. 2015;36(5):245-52. doi:10.4082/kjfm.2015.36.5.245 | | | X
1008 | Upadya H, Devaraju CJ, Joshi SR. Anti-inflammatory properties of blended edible oil with synergistic antioxidants. Indian J Endocrinol Metab. 2015;19(4):511-9. doi:10.4103/2230-8210.159063 | | | | Health Status, Country
1009 | Uusitalo L, Nevalainen J, Salminen I, et al. Fatty acids in serum and diet--a canonical correlation analysis among toddlers. Matern Child Nutr. 2013;9(3):381-95. doi:10.1111/j.1740-8709.2011.00374.x | | | X
1010 | Uusitupa M, Hermansen K, Savolainen MJ, et al. Effects of an isocaloric healthy Nordic diet on insulin sensitivity, lipid profile and inflammation markers in metabolic syndrome -- a randomized study (SYSDIET). J Intern Med. 2013;274(1):52-66. doi:10.1111/joim.12044 | | X
1011 | Valente FX, Candido FG, Lopes LL, et al. Effects of coconut oil consumption on energy metabolism, cardiometabolic risk markers, and appetitive responses in women with excess body fat. Eur J Nutr. 2018;57(4):1627-1637. doi:10.1007/s00394-017-1448-5 | | | X
1012 | Valera B, Suhas E, Counil E, Poirier P, Dewailly E. Influence of polyunsaturated fatty acids on blood pressure, resting heart rate and heart rate variability among French Polynesians. J Am Coll Nutr. 2014. 33(4):288-296. doi:10.1080/07315724.2013.874913 | X | X
1013 | Valsta LM, Jauhiainen M, Aro A, Katan MB, Mutanen M. Effects of a monounsaturated rapeseed oil and a polyunsaturated sunflower oil diet on lipoprotein levels in humans. Arterioscler Thromb.1992. 12(1):50-7. doi:10.1161/01.atv.12.1.50 | | | | Age of participants at intervention or exposure
1014 | van der Gaag EJ, Wieffer R, van der Kraats J. Advising consumption of green vegetables, beef, and full-fat dairy products has no adverse effects on the lipid profiles in children. Nutrients. 2017. 9(5). pii: E518. doi:10.3390/nu9050518 | | X
1015 | van Hees AM, Saris WH, Hul GB, et al. Effects of dietary fat modification on skeletal muscle fatty acid handling in the metabolic syndrome. Int J Obes (Lond). 2010. 34(5):859-70. doi:10.1038/ijo.2010.6 | | | | Duplicate data
1016 | Van Rooijen M, Plat J, Blom W, Zock P, Mensink R. The saturated fatty acids palmitic acid and stearic acid do not differently affect cholesterol efflux capacity: Results of A human dietary intervention trial. Atherosclerosis. 2019;287e56- . doi:10.1016/j.atherosclerosis.2019.06.159 | | | | Publication Status
1017 | Varady KA, Dam VT, Klempel MC, et al. Effects of weight loss via high fat vs. low fat alternate day fasting diets on free fatty acid profiles. Sci Rep. 2015. 5:7561. doi:10.1038/srep07561 | | X
1018 | Vasilopoulou D, Markey O, Fagan CC, et al. Chronic consumption of conventional and saturated-fat reduced dairy products have differential effects on low-density lipoprotein cholesterol levels in adults at moderate cardiovascular disease risk. Proceedings of the Nutrition Society. 2016;75(OCE3):E169. doi:10.1017/S0029665116001841 | | | | Publication Status
1019 | Vedtofte MS, Jakobsen MU, Lauritzen L, et al. Association between the intake of alpha-linolenic acid and the risk of CHD. Br J Nutr. 2014;112(5):735-43. doi:10.1017/s000711451400138x | X
1020 | Velazquez-Lopez L, Santiago-Diaz G, Nava-Hernandez J, Munoz-Torres AV, Medina-Bravo P, Torres-Tamayo M. Mediterranean-style diet reduces metabolic syndrome components in obese children and adolescents with obesity. BMC Pediatr. 2014;14:175. doi:10.1186/1471-2431-14-175 | | X
1021 | Venkatramanan S, Joseph SV, Chouinard PY, Jacques H, Farnworth ER, Jones PJ. Milk enriched with conjugated linoleic acid fails to alter blood lipids or body composition in moderately overweight, borderline hyperlipidemic individuals. J Am Coll Nutr. 2010;29(2):152-9. doi:10.1080/07315724.2010.10719829 | | X | | Health Status
1022 | Viikari J, Akerblom HK, Rasanen L, Kalavainen M, Pietarinen O. Cardiovascular risk in young Finns. Experiences from the Finnish Multicentre Study regarding the prevention of coronary heart disease. Acta Paediatr Scand Suppl. 1990. 365:13-9. doi:10.1111/j.1651-2227.1990.tb11579.x | X
1023 | Vildmyren I, Halstensen A, Oterhals A, Gudbrandsen OA. Cod protein powder lowered serum nonesterified fatty acids and increased total bile acid concentrations in healthy, lean, physically active adults: A randomized double-blind study. Food Nutr Res. 2019;63. doi:10.29219/fnr.v63.3437 | | X
1024 | Villalpando S, Lara Zamudio Y, Shamah-Levy T, Mundo-Rosas V, Manzano AC, Lamadrid-Figueroa H. Substitution of whole cows’ milk with defatted milk for 4 months reduced serum total cholesterol HDL-cholesterol and total apoB in a sample of Mexican school-age children (6-16 years of age). Br J Nutr. 2015. 114(5):788-95. doi:10.1017/s0007114515002330 | | X
1025 | Villamor E, Marin C, Mora-Plazas M, Casale M, Vargas LN, Baylin A. Cooking with soyabean oil increases whole-blood alpha-linolenic acid in school-aged children: Results from a randomized trial. Public Health Nutr. 2015;18(18):3420-8. doi:10.1017/s1368980015000762 | | | X
1026 | Villaverde P, Lajous M, MacDonald CJ, Fagherazzi G, Bonnet F, Boutron-Ruault MC. High dietary total antioxidant capacity is associated with a reduced risk of hypertension in French women. Nutr J. 2019;18(1):31. doi:10.1186/s12937-019-0456-0 | | X
1027 | Vincent MJ, Allen B, Palacios OM, Haber LT, Maki KC. Meta-regression analysis of the effects of dietary cholesterol intake on LDL and HDL cholesterol. Am J Clin Nutr. 2019;109(1):7-16. doi:10.1093/ajcn/nqy273 | X
1028 | Violi F, Loffredo L, Pignatelli P, et al. Extra virgin olive oil use is associated with improved post-prandial blood glucose and LDL cholesterol in healthy subjects. Nutr Diabetes. 2015;5e172. doi:10.1038/nutd.2015.23 | | | X
1029 | Vishwanathan R, Gendron CM, Goodrow-Kotyla EF, Wilson TA, Nicolosi RJ. Increased consumption of dietary cholesterolluteinand zeaxanthin as egg yolks does not decrease serum concentrations and lipoprotein distribution of other carotenoidsretinoland tocopherols. Nutr Res. 2010;30(11):747-55. doi:10.1016/j.nutres.2010.10.007 | | X | X
1030 | Vissers LET, Waller M, van der Schouw YT, et al. A pro-inflammatory diet is associated with increased risk of developing hypertension among middle-aged women. Nutr Metab Cardiovasc Dis. 2017;27(6):564-570. doi:10.1016/j.numecd.2017.03.005 | | X
1031 | Viturro E, de Oya M, Lasuncion MA, et al. Cholesterol and saturated fat intake determine the effect of polymorphisms at ABCG5/ABCG8 genes on lipid levels in children. Genet Med. 2006. 8(9):594-9. doi:10.109701.gim.0000237760.25195.e7 | X | X
1032 | von Ruesten A, Feller S, Bergmann MM, Boeing H. Diet and risk of chronic diseases: Results from the first 8 years of follow-up in the EPIC-Potsdam study. Eur J Clin Nutr. 2013;67(4):412-9. doi:10.1038/ejcn.2013.7 | | X
1033 | Voortman T, Kiefte-de Jong JC, Ikram MA, et al. Adherence to the 2015 Dutch dietary guidelines and risk of non-communicable diseases and mortality in the Rotterdam Study. Eur J Epidemiol. 2017;32(11):993-1005. doi:10.1007/s10654-017-0295-2 | | X
1034 | Vors C, Joumard-Cubizolles L, Lecomte M, et al. Milk polar lipids reduce lipid cardiovascular risk factors in overweight postmenopausal women: Towards a gut sphingomyelin-cholesterol interplay. Gut. 2019;69(3):487-501. doi:10.1136/gutjnl-2018-318155 | | X | | Health Status
1035 | Vorster HH, Benade AJ, Barnard HC, et al. Egg intake does not change plasma lipoprotein and coagulation profiles. Am J Clin Nutr.1992. 55(2):400-10. doi:10.1093/ajcn/55.2.400 | | | | Age of participants at intervention or exposure
1036 | Vyncke K, Huybrechts I, Van Winckel M, et al. Dietary lipid intake only partially influences variance in serum phospholipid fatty acid composition in adolescents: Impact of other dietary factors. Lipids. 2014;49(9):881-93. doi:10.1007/s11745-014-3935-2 | X | | X
1037 | Wade AT, Davis CR, Dyer KA, Hodgson JM, Woodman RJ, Murphy KJ. A Mediterranean diet supplemented with dairy foods improves markers of cardiovascular risk: Results from the MedDairy randomized controlled trial. Am J Clin Nutr. 2018;108(6):1166-1182. doi:10.1093/ajcn/nqy207 | | X
1038 | Wan Y, Wang F, Yuan J, et al. Effects of dietary fat on gut microbiota and faecal metabolitesand their relationship with cardiometabolic risk factors: A 6-month randomised controlled-feeding trial. Gut. 2019;68(8):1417-1429. doi:10.1136/gutjnl-2018-317609 | | X | X
1039 | Wan Y, Yuan J, Li J, et al. Unconjugated and secondary bile acid profiles in response to higher-fat, lower-carbohydrate diet and associated with related gut microbiota: A 6-month randomized controlled-feeding trial. Clin Nutr. 2019;39(2):395-404. doi:10.1016/j.clnu.2019.02.037 | | X | X
1040 | Wanders AJ, Brouwer IA, Siebelink E, Katan MB. Effect of a high intake of conjugated linoleic acid on lipoprotein levels in healthy human subjects. PLoS One. 2010;5(2):e9000. doi:10.1371/journal.pone.0009000 | | X
1041 | Wang D, Campos H, Baylin A. Red meat intake is positively associated with non-fatal acute myocardial infarction in the Costa Rica Heart Study. Br J Nutr. 2017;118(4):303-311. doi:10.1017/s000711451700201x | X
1042 | Wang DD, Toledo E, Hruby A, et al. Plasma ceramides, Mediterranean diet, and incident cardiovascular disease in the PREDIMED trial (prevención con dieta mediterránea). Circulation. 2017;135(21):2028-2040. doi:10.1161/CIRCULATIONAHA.116.024261 | | X
1043 | Wang DD, Zheng Y, Toledo E, et al. Lipid metabolic networks, Mediterranean diet and cardiovascular disease in the PREDIMED trial. Int J Epidemiol. 2018. 47(6):1830-1845. doi:10.1093/ije/dyy198 | X | X
1044 | Wang H, Fox CS, Troy LM, McKeown NM, Jacques PF. Longitudinal association of dairy consumption with the changes in blood pressure and the risk of incident hypertension: The Framingham Heart Study. Br J Nutr. 2015;114(11):1887-99. doi:10.1017/s0007114515003578 | | X
1045 | Wang L, Manson JE, Forman JP, Gaziano JM, Buring JE, Sesso HD. Dietary fatty acids and the risk of hypertension in middle-aged and older women. Hypertension. 2010;56(4):598-604. doi:10.1161/hypertensionaha.110.154187 | | | X
1046 | Wang L, Tao L, Hao L, et al. A Moderate-fat diet with one avocado per day increases plasma antioxidants and decreases the oxidation of small, dense LDL in adults with overweight and obesity: A randomized controlled trial. J Nutr. 2019;150(2):276-284. doi:10.1093/jn/nxz231 | | | X
1047 | Wang MP, Thomas GN, Ho SY, Lai HK, Mak KH, Lam TH. Fish consumption and mortality in Hong Kong Chinese--the LIMOR study. Ann Epidemiol. 2011;21(3):164-9. doi:10.1016/j.annepidem.2010.10.010 | | X
1048 | Wannamethee SG, Jefferis BJ, Lennon L, Papacosta O, Whincup PH, Hingorani AD. Serum conjugated linoleic acid and risk of incident heart failure in older men: The British Regional Heart Study. J Am Heart Assoc. 2018;7(1). pii: e006653. doi:10.1161/jaha.117.006653 | | X
1049 | Ward RE, Cho K, Nguyen XT, et al. Omega-3 supplement usefish intakeand risk of non-fatal coronary artery disease and ischemic stroke in the Million Veteran Program. Clin Nutr. 2019;39(2):574-579. doi:10.1016/j.clnu.2019.03.005 | | X
1050 | Weech M, Altowaijri H, Mayneris-Perxachs J, et al. Replacement of dietary saturated fat with unsaturated fats increases numbers of circulating endothelial progenitor cells and decreases numbers of microparticles: findings from the randomized, controlled Dietary Intervention and VAScular function (DIVAS) study. Am J Clin Nutr. 2018;107(6):876-882. doi:10.1093/ajcn/nqy018 | | | X
1051 | Weech M, Vafeiadou K, Hasaj M, et al. Development of a foodexchange model to replace saturated fat with MUFAs and n-6 PUFAs in adults at moderate cardiovascular risk. J Nutr. 2014;144(6):846-55. doi:10.3945/jn.114.190645 | | | X
1052 | Weech M, Vafeiadou K, Mihaylova R, et al. Substitution of dietary saturated fatty acids with either monounsaturated or n-6 polyunsaturated fatty acids improves the plasma lipid profile in those at risk from CVD: results from the DIVAS study. Proceedings of the nutrition society.2013. 72.E182. doi:10.1017/S0029665113002073 | | | | Publication Status
1053 | Weech M, Vafeiadou K, Todd S, Yaqoob P, Jackson KG, Lovegrove JA. Replacing dietary saturated with unsaturated fat reduces the cardiovascular risk score in men and women at moderate cardiovascular risk: DIVAS study. Proceedings of the nutrition society. 2015;74(OCE1): E123. doi:10.1017/S002966511500138X | | | | Publication Status
1054 | Weggemans RM, Zock PL, Ordovas JM, Pedro-Botet J, Katan MB. Apoprotein E genotype and the response of serum cholesterol to dietary fat, cholesterol and cafestol. Atherosclerosis. 2001. 154(3):547-555. doi:10.1016/S0021-9150(00)00720-6 | | | | Age of participants at intervention or exposure
1055 | Weihua Mmed L, Yougang W, Jing W. Reduced or modified dietary fat for preventing cardiovascular disease. J Cardiovasc Nurs. 2013;28(3):204-5. doi:10.1097/JCN.0b013e3182816005 | X
1056 | West CE, Sullivan DR, Katan MB, Halferkamps IL, van der Torre HW. Boys from populations with high-carbohydrate intake have higher fasting triglyceride levels than boys from populations with high-fat intake. Am J Epidemiol. 1990. 131(2):271-82. doi:10.1093/oxfordjournals.aje.a115497 | X
1057 | West SG, Gebauer SK, Kay CD, et al. Diets containing pistachios reduce systolic blood pressure and peripheral vascular responses to stress in adults with dyslipidemia. Hypertension. 2012;60(1):58-63. doi:10.1161/hypertensionaha.111.182147 | | | | Health Status
1058 | West SG, Krick AL, Klein LC, et al. Effects of diets high in walnuts and flax oil on hemodynamic responses to stress and vascular endothelial function. J Am Coll Nutr. 2010;29(6):595-603. doi:10.1080/07315724.2010.10719898 | | | | Health Status
1059 | White AA, Klimis-Tavantzis DJ. Dietary risk assessment for cardiovascular disease among central Maine adolescents. J Sch Health. 1992. 62(9):428-32. doi:10.1111/j.1746-1561.1992.tb01262.x | X | | X
1060 | Williams PT, Bergeron N, Chiu S, Krauss RM. A randomized, controlled trial on the effects of almonds on lipoprotein response to a higher carbohydrate, lower fat diet in men and women with abdominal adiposity. Lipids Health Dis. 2019;18(1):83. doi:10.1186/s12944-019-1025-4 | | | X | Study Duration
1061 | Wilson DK, Lewis NM. Weight-for-height measurement and saturated fatty acid intake are predictors of serum cholesterol level in children. J Am Diet Assoc. 1992. 92(2):192-6. | X
1062 | Winkvist A, Klingberg S, Nilsson LM, et al. Longitudinal 10-year changes in dietary intake and associations with cardio-metabolic risk factors in the Northern Sweden Health and Disease Study. Nutr J. 2017;16(1):20. doi:10.1186/s12937-017-0241-x | | | X
1063 | Wolff E, Vergnes MF, Portugal H, et al. Cholesterol-absorber status modifies the LDL cholesterol-lowering effect of a Mediterranean-type diet in adults with moderate cardiovascular risk factors. J Nutr. 2011;141(10):1791-8. doi:10.3945/jn.111.141333 | | X
1064 | Wong H, Chahal N, Manlhiot C, Niedra E, McCrindle BW. Flaxseed in pediatric hyperlipidemia: a placebo-controlled, blinded, randomized clinical trial of dietary flaxseed supplementation for children and adolescents with hypercholesterolemia. JAMA Pediatr. 2013;167(8):708-13. doi:10.1001/jamapediatrics.2013.1442 | | X | | Health Status
1065 | Wong VCH, Maguire JL, Omand JA, et al. A Positive Association Between Dietary Intake of Higher Cow’s Milk-Fat Percentage and Non-High-Density Lipoprotein Cholesterol in Young Children. J Pediatr. 2019;211105-111.e2. doi:10.1016/j.jpeds.2019.03.047 | | X
1066 | Wong WW, Hachey DL, Insull W, Opekun AR, Klein PD. Effect of dietary cholesterol on cholesterol synthesis in breast-fed and formula-fed infants. J Lipid Res. 1993. 34(8):1403-11. | | X
1067 | Wu Y, Sun G, Zhou X, et al. Pregnancy dietary cholesterol intake, major dietary cholesterol sourcesand the risk of gestational diabetes mellitus: A prospective cohort study. Clin Nutr. 2019; 5614(19)30272-9. doi:10.1016/j.clnu.2019.06.016 | | | X
1068 | Wulan SN, Westerterp KR, Plasqui G. Metabolic profile before and after short-term overfeeding with a high-fat diet: A comparison between South Asian and white men. British Journal of Nutrition. 2014;111(10):1853-1861. doi:10.1017/S0007114514000014 | | X
1069 | Wurtz AM, Hansen MD, Tjonneland A, et al. Substitution of meat and fish with vegetables or potatoes and risk of myocardial infarction. Br J Nutr. 2016;116(9):1602-1610. doi:10.1017/s0007114516003500 | | X
1070 | Wurtz AM, Hansen MD, Tjonneland A, et al. Substitutions of red meat poultry and fish and risk of myocardial infarction. Br J Nutr. 2016;115(9):1571-8. doi:10.1017/s0007114516000507 | | X
1071 | Xu Y, Wahlberg K, Love TM, et al. Associations of blood mercury and fatty acid concentrations with blood mitochondrial DNA copy number in the Seychelles Child Development Nutrition Study. Environ Int. 2019;124278-283. doi:10.1016/j.envint.2019.01.019 | | X | X
1072 | Xun P, Hou N, Daviglus M, et al. Fish oilselenium and mercury in relation to incidence of hypertension: a 20-year follow-up study. J Intern Med. 2011;270(2):175-86. doi:10.1111/j.1365-2796.2010.02338.x | | | X
1073 | Yaemsiri S, Sen S, Tinker LF, et al. Serum fatty acids and incidence of ischemic stroke among postmenopausal women. Stroke. 2013;44(10):2710-7. doi:10.1161/strokeaha.111.000834 | | X
1074 | Yagalla MV, Hoerr SL, Song WO, Enas E, Garg A. Relationship of dietabdominal obesity, and physical activity to plasma lipoprotein levels in Asian Indian physicians residing in the United States. Journal of the American Dietetic Association. 1996. 96(3):257-261. | | | | Age of participants at intervention or exposure
1075 | Yamagishi K, Iso H, Shimazu T, et al. Fish intake and risk of mortality due to aortic dissection and aneurysm: A pooled analysis of the Japan cohort consortium. Clin Nutr. 2019;38(4):1678-1683. doi:10.1016/j.clnu.2018.08.007 | X | X
1076 | Yamanaka M, Sakuma M, Matsushita A, et al. The Effects of Long-Term Dietary Therapy on Patients with Hypertriglyceridemia. J Atheroscler Thromb. 2019;26(1):39-49. doi:10.5551/jat.42440 | | X | | Health Status
1077 | Yao Y, Liu W, Zhou H, et al. The Relations between Minor Components and Antioxidant Capacity of Five Fruits and Vegetables Seed Oils in China. J Oleo Sci. 2019;68(7):625-635. doi:10.5650/jos.ess19005 | | | X
1078 | Yu D, Sonderman J, Buchowski MS, et al. Healthy Eating and Risks of Total and Cause-Specific Death among Low-Income Populations of African-Americans and Other Adults in the Southeastern United States: A Prospective Cohort Study. PLoS Med. 2015;12(5):e1001830; discussion e1001830. doi:10.1371/journal.pmed.1001830 | | X
1079 | Yu E, Ruiz-Canela M, Guasch-Ferre M, et al. Increases in Plasma Tryptophan Are Inversely Associated with Incident Cardiovascular Disease in the Prevencion con Dieta Mediterranea (PREDIMED) Study. J Nutr. 2017;147(3):314-322. doi:10.3945/jn.116.241711 | | X
1080 | Zacek P, Bukowski M, Johnson L, Raatz SK, Picklo M. Selective enrichment of n-3 fatty acids in human plasma lipid motifs following intake of marine fish. J Nutr Biochem. 2018;5457-65. doi:10.1016/j.jnutbio.2017.11.002 | | | X
1081 | Zarrazquin I, Torres-Unda J, Ruiz F, et al. Longitudinal study: lifestyle and cardiovascular health in health science students. Nutr Hosp. 2014;30(5):1144-51. doi:10.3305/nh.2014.30.5.7833 | X
1082 | Zhang B, Guglielmo B, Furtado JD, Sacks FM. Unsaturated fat replacing carbohydrate or protein affects protein-based HDL subspecies of different functionality. Circulation. 2019;139. doi:10.1161/circ.139.suppl_1.P200 | | | | Publication Status
1083 | Zhang HW, Zhao X, Guo YL, et al. Free fatty acids and cardiovascular outcome: a Chinese cohort study on stable coronary artery disease. Nutr Metab (Lond). 2017;14(41). doi:10.1186/s12986-017-0195-1 | | X
1084 | Zhang J, Wang C, Li L, et al. Dietary inclusion of salmon, herring and pompano as oily fish reduces CVD risk markers in dyslipidaemic middle-aged and elderly Chinese women. Br J Nutr. 2012;108(8):1455-65. doi:10.1017/s0007114511006866 | | | | Health Status
1085 | Zhang J, Wang C, Li L, et al. Inclusion of Atlantic salmon in the Chinese diet reduces cardiovascular disease risk markers in dyslipidemic adult men. Nutr Res. 2010;30(7):447-54. doi:10.1016/j.nutres.2010.06.010 | | X | | Country
1086 | Zhang S, Lin X, Lynn H, et al. Dietary cholesterol interacts with SREBF1 to modulate obesity in Chinese children. Mol Nutr Food Res. 2017;61(9). doi:10.1002/mnfr.201700105 | X
1087 | Zhang X, Qi Q, Bray GA, Hu FB, Sacks FM, Qi L. APOA5 genotype modulates 2-y changes in lipid profile in response to weight-loss diet intervention: the Pounds Lost Trial. Am J Clin Nutr. 2012;96(4):917-22. doi:10.3945/ajcn.112.040907 | | X
1088 | Zhang Z, Gillespie C, Yang Q. Plasma trans-fatty acid concentrations continue to be associated with metabolic syndrome among US adults after reductions in trans-fatty acid intake. Nutr Res. 2017;4351-59. doi:10.1016/j.nutres.2017.05.008 | X | X
1089 | Zhang Z, Lanza E, Kris-Etherton PM, et al. A high legume low glycemic index diet improves serum lipid profiles in men. Lipids. 2010;45(9):765-75. doi:10.1007/s11745-010-3463-7 | | X
1090 | Zhao JV, Schooling CM. Effect of linoleic acid on ischemic heart disease and its risk factors: a Mendelian randomization study. BMC Med. 2019;17(1):61. doi:10.1186/s12916-019-1293-x | X | X
1091 | Zheng Y, Yu B, Alexander D, Steffen LM, Boerwinkle E. Human metabolome associates with dietary intake habits among African Americans in the atherosclerosis risk in communities study. Am J Epidemiol. 2014;179(12):1424-33. doi:10.1093/aje/kwu073 | | X | X
1092 | Zhong H, Penders J, Shi Z, et al. Impact of early events and lifestyle on the gut microbiota and metabolic phenotypes in young school-age children. Microbiome. 2019;7(1):2. doi:10.1186/s40168-018-0608-z | | X | X
1093 | Zhou YB, Li HT, Trasande L, et al. A Correlation Study of DHA Intake Estimated by a FFQ and Concentrations in Plasma and Erythrocytes in Mid- and Late Pregnancy. Nutrients. 2017;9(11): pii: E1256. doi:10.3390/nu9111256 | X | | X
1094 | Zhu WL, Feng NP, Ma J, Wang Y, Ye GJ. The effect of dietary intervention on lipidemia in school-aged children. Zhonghua liu xing bing xue za zhi. 2003. 24(9):794- 797. | | | | Language
1095 | Zhu YH, Jeong S, Wu M, et al. Dietary Intake of Fatty AcidsTotal Cholesteroland Stomach Cancer in a Chinese Population. Nutrients. 2019;11(8): pii: E1730. doi:10.3390/nu11081730 | | | X
1096 | Zhu Z, Wu F, Lu Y, et al. The association of dietary cholesterol and fatty acids with dyslipidemia in Chinese metropolitan men and women. Nutrients. 2018;10(8): pii: E961. doi:10.3390/nu10080961 | X
1097 | Zibaeenezhad MJ, Ghavipisheh M, Attar A, Aslani A. Comparison of the effect of omega-3 supplements and fresh fish on lipid profile: a randomizedopen-labeled trial. Nutr Diabetes. 2017;7(12):1. doi:10.1038/s41387-017-0007-8 | | X
1098 | Zibaeenezhad MJ, Ostovan P, Mosavat SH, Zamirian M, Attar A. Almond oil for patients with hyperlipidemia: A randomized open-label controlled clinical trial. Complement Ther Med. 2019;42:33-36. doi:10.1016/j.ctim.2018.10.013 | | | | Health Status
1099 | Zinn C, McPhee J, Harris N, Williden M, Prendergast K, Schofield G. A 12-week low-carbohydratehigh-fat diet improves metabolic health outcomes over a control diet in a randomised controlled trial with overweight defence force personnel. Appl Physiol Nutr Metab. 2017;42(11):1158-1164. doi:10.1139/apnm-2017-0260 | | X
1100 | Zock PL, de Vries JH, Katan MB. Impact of myristic acid versus palmitic acid on serum lipid and lipoprotein levels in healthy women and men. Arterioscler Thromb. 1994. 14(4):567-75. | | | | Age of participants at intervention or exposure
1101 | Zock PL, Katan MB. Hydrogenation alternatives: effects of trans fatty acids and stearic acid versus linoleic acid on serum lipids and lipoproteins in humans. J Lipid Res. 1992. 33(3):399-410. | | | | Age of participants at intervention or exposure
1102 | Zong G, Sun Q, Yu D, et al. Dairy consumptiontype 2 diabetesand changes in cardiometabolic traits: A prospective cohort study of middle-aged and older chinese in beijing and shanghai. Diabetes Care. 2014;37(1):56-63. doi:10.2337/dc13-0975 | | X
1103 | Zubair N, Kuzawa CW, Lee NR, McDade TW, Adair LS. Clustering and determinants of cardiometabolic risk factors among Filipino young adults. Asia Pac J Clin Nutr. 2014;23(1):148-58. doi:10.6133/apjcn.2014.23.1.06 | | | | Country

* This table presents the combined list of articles excluded after full text screening from both searches. As stated previously, the search results from both search strategies (described in the Electronic databases and search terms) were combined for efficiency and screened together in screening software by two analysts independently because both searches addressed the same overall systematic review question from different search date ranges.

xii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xiii Dietary Guidelines Advisory Committee. 2015. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. U.S. Department of Agriculture, Agricultural Research Service, Washington, D.C.