# WHAT IS THE RELATIONSHIP BETWEEN TYPES OF DIETARY FAT CONSUMED AND RISK OF CARDIOVASCULAR DISEASE?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between types of dietary fat consumed and risk of cardiovascular disease?

### What is the answer to the question?

Cardiovascular disease intermediate outcomes (blood lipids and blood pressure): Children

- Strong evidence demonstrates that diets lower in saturated fatty acids and cholesterol during childhood result in lower levels of total blood and low-density lipoprotein cholesterol throughout childhood, particularly in boys.
- Moderate evidence indicates that diets higher in polyunsaturated fatty acids during childhood result in lower levels of total blood cholesterol throughout childhood, particularly in boys.
- Insufficient evidence is available to determine the relationship between monounsaturated fatty acid intake during childhood and total blood and low-density lipoprotein cholesterol throughout childhood.
- Insufficient evidence is available to determine the relationship between intake of types of dietary fat during childhood and blood pressure throughout childhood.

Cardiovascular disease endpoint outcomes (cardiovascular disease event, diagnosis, or mortality): Children

- Insufficient evidence is available to determine the relationship between intake of types of dietary fat during childhood and cardiovascular disease health outcomes during adulthood.

Cardiovascular disease intermediate outcomes (blood lipids): Adults

- Strong and consistent evidence from randomized controlled trials demonstrates that replacing saturated fatty acids with unsaturated fats, especially polyunsaturated fatty acids, in adults significantly reduces total and low-density lipoprotein cholesterol. Replacing saturated fatty acids with carbohydrates (sources not defined) also reduces total and low-density lipoprotein cholesterol, but significantly increases triglycerides and reduces high-density lipoprotein cholesterol. Since the 2015 Dietary Guidelines Advisory Committee review, evidence remains inadequate to differentiate among sources of carbohydrate and their impact on blood lipids.
- Insufficient evidence is available to determine an independent relationship between dietary cholesterol intake in adults and blood lipids, given the co-occurrence of cholesterol with saturated fats in foods.

Cardiovascular disease endpoint outcomes (cardiovascular disease event, diagnosis, or mortality): Adults

- Strong evidence demonstrates that replacing saturated fatty acids with polyunsaturated fatty acids in adults reduces the risk of coronary heart disease events and cardiovascular disease mortality.
- Insufficient evidence is available to determine whether replacing saturated fatty acids with polyunsaturated fatty acids in adults affects the risk of stroke or heart failure.
- Insufficient evidence is available to determine whether replacing saturated fatty acids with different types of carbohydrates (e.g., complex, simple) in adults affects the risk of cardiovascular disease.
- Limited evidence is available regarding whether replacing saturated fatty acids with monounsaturated fatty acids in adults confers overall cardiovascular disease endpoint health benefits. Main sources of monounsaturated fatty acids in a typical American diet are animal fats, with co-occurrence of saturated fatty acids and monounsaturated fatty acids in these foods thereby obscuring the independent association of monounsaturated fatty acids with cardiovascular disease. Evidence reviewed from randomized controlled trials and prospective studies demonstrated benefits of plant sources of monounsaturated fats, including olive oil and nuts on cardiovascular disease risk.
- Moderate evidence indicates that total intake of omega-3 polyunsaturated fatty acids, particularly eicosapentaenoic acid and docosahexaenoic acid from food sources, by adults is associated with lower risk of cardiovascular disease.
- Limited evidence suggests that intake of linoleic acid, but not arachidonic acid, during adulthood may be associated with lower risk of cardiovascular disease, including cardiovascular disease mortality.
- Insufficient evidence is available from randomized controlled trials to quantify an independent relationship between dietary cholesterol intake in adults and overall risk of cardiovascular disease.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Dietary Fats and Seafood Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.

### What is the population of interest?

- For the intervention or exposure, generally healthy children, age 18 years and younger, and adults, age 19 years and older. For the outcome, those who had blood pressure measured during childhood, blood lipids measured during childhood or adulthood, and/or had CVD endpoint outcomes measured during adulthood.

### What evidence was found?

- This review identified 228 articles that met inclusion criteria: 37 in children and 191 in adults.
- Children:
  ○ Most studies found that lower childhood intake of saturated fatty acids (SFA) and dietary cholesterol, as well as higher intake of polyunsaturated fatty acids (PUFA), were beneficial for total blood cholesterol and/or low-density lipoprotein (LDL) cholesterol. Results were more consistent in boys. The 2020 Committee determined this evidence was strong for SFA and dietary cholesterol and moderate for PUFA.
  ○ Few studies examined monounsaturated fatty acid (MUFA) intake during childhood and its relationship to blood lipids and a conclusion could not be drawn.
  ○ Few studies examined types of dietary fat during childhood and either blood pressure or risk of CVD and a conclusion could not be drawn.
- Adults:
  ○ Most studies reported a beneficial effect of replacing SFA with MUFA or PUFA on total and LDL cholesterol. Most studies did not find an effect of replacing SFA with MUFA or PUFA on high-density lipoprotein (HDL) cholesterol or triglycerides.
  ○ Many studies found that replacement of SFA with PUFA was related to lower risk of CVD mortality and CHD. No consistent relationship between replacement of SFA with MUFA or carbohydrates and risk of CVD was found.
  ○ The 2020 Committee could not draw a conclusion about replacement of SFA with PUFA and heart failure or stroke due to a lack of evidence.
  ○ Several studies observed a beneficial relationship between higher omega-3 PUFA intake and lower risk of CVD, most consistently for eicosapentaenoic acid (EPA) and docosahexaenoic acid (DHA).
  ○ Few studies assessed the relationship between omega-6 PUFA intake and risk of CVD, tending to observe benefits with higher intake of linoleic acid but not with arachidonic acid.
  ○ The 2020 Committee could not draw a conclusion about the relationship between dietary cholesterol intake and blood lipids or risk of CVD due to a small number of studies and inconsistent results. Additionally, dietary cholesterol is commonly found in foods that also contain SFA, making it difficult to assess dietary cholesterol independently.
  ○ This systematic review builds and expands on the work of the 2015 Committee. The 2020 Committee concurs with and updates the conclusions drawn by the 2015 Committee.

### How up-to-date is this systematic review?

This review searched for studies in children from January 1990 to October 2019 and studies in adults from January 2010 to October 2019.

## TECHNICAL ABSTRACT

### Background

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.
- The 2020 Dietary Guidelines Advisory Committee, Dietary Fats and Seafood Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- The goal of this systematic review was to examine the following question: What is the relationship between types of dietary fat consumed and risk of cardiovascular disease?

### Conclusion statements and grades

- Cardiovascular disease intermediate outcomes: Children
  - Strong evidence demonstrates that diets lower in saturated fatty acids and cholesterol during childhood result in lower levels of total blood and low-density lipoprotein cholesterol throughout childhood, particularly in boys. (Grade: Strong)
  - Moderate evidence indicates that diets higher in polyunsaturated fatty acids during childhood result in lower levels of total blood cholesterol throughout childhood, particularly in boys. (Grade: Moderate)
  - Insufficient evidence is available to determine the relationship between monounsaturated fatty acid intake during childhood and total blood and low-density lipoprotein cholesterol throughout childhood. (Grade: Grade not assignable)
  - Insufficient evidence is available to determine the relationship between intake of types of dietary fat during childhood and blood pressure throughout childhood. (Grade: Grade not assignable)
- Cardiovascular disease endpoint outcomes: Children
  - Insufficient evidence is available to determine the relationship between intake of types of dietary fat during childhood and cardiovascular disease health outcomes during adulthood. (Grade: Grade not assignable)
- Cardiovascular disease intermediate outcomes: Adults
  - Strong and consistent evidence from randomized controlled trials demonstrates that replacing saturated fatty acids with unsaturated fats, especially polyunsaturated fatty acids, in adults significantly reduces total and low-density lipoprotein cholesterol. Replacing saturated fatty acids with carbohydrates (sources not defined) also reduces total and low-density lipoprotein cholesterol, but significantly increases triglycerides and reduces high-density lipoprotein cholesterol. Since the 2015 Dietary Guidelines Advisory Committee review, evidence remains inadequate to differentiate among sources of carbohydrate and their impact on blood lipids. (Grade: Strong)
  - Insufficient evidence is available to determine an independent relationship between dietary cholesterol intake in adults and blood lipids, given the co-occurrence of cholesterol with saturated fats in foods. (Grade: Grade not assignable)
- Cardiovascular disease endpoint outcomes: Adults
  - Strong evidence demonstrates that replacing saturated fatty acids with polyunsaturated fatty acids in adults reduces the risk of coronary heart disease events and cardiovascular disease mortality. (Grade: Strong)
  - Insufficient evidence is available to determine whether replacing saturated fatty acids with polyunsaturated fatty acids in adults affects the risk of stroke or heart failure. (Grade: Grade not assignable)
  - Insufficient evidence is available to determine whether replacing saturated fatty acids with different types of carbohydrates (e.g., complex, simple) in adults affects the risk of cardiovascular disease. (Grade: Grade not assignable)
  - Limited evidence is available regarding whether replacing saturated fatty acids with monounsaturated fatty acids in adults confers overall cardiovascular disease endpoint health benefits. Main sources of monounsaturated fatty acids in a typical American diet are animal fats, with co-occurrence of saturated fatty acids and monounsaturated fatty acids in these foods thereby obscuring the independent association of monounsaturated fatty acids with cardiovascular disease. Evidence reviewed from randomized controlled trials and prospective studies demonstrated benefits of plant sources of monounsaturated fats, including olive oil and nuts on cardiovascular disease risk. (Grade: Limited)
  - Moderate evidence indicates that total intake of omega-3 polyunsaturated fatty acids, particularly eicosapentaenoic acid and docosahexaenoic acid from food sources, by adults is associated with lower risk of cardiovascular disease. (Grade: Moderate)
  - Limited evidence suggests that intake of linoleic acid, but not arachidonic acid, during adulthood may be associated with lower risk of cardiovascular disease, including cardiovascular disease mortality. (Grade: Limited)
  - Insufficient evidence is available from randomized controlled trials to quantify an independent relationship between dietary cholesterol intake in adults and overall risk of cardiovascular disease. (Grade: Grade not assignable)

### Methods

- Two literature searches were conducted using 4 databases (PubMed, Cochrane, Embase, CINAHL) to identify articles that evaluated the intervention or exposure of intake of types of dietary fat and the outcomes of cardiovascular disease (CVD) intermediate outcomes (blood lipids in children and adults; blood pressure in children) and CVD endpoint outcomes. Because this systematic review built on evidence reviewed by the 2015 Dietary Guidelines Advisory Committee, one search was designed to identify articles in children from January 1990 to December 2009 and the other search was designed to identify articles in children and adults from January 2010 to October 2019. A manual search was conducted to identify articles that may not have been included in the electronic databases searched. Articles were screened by two NESR analysts independently for inclusion based on pre-determined criteria.
- Data extraction and risk of bias assessment were conducted for each included study, and both were checked for accuracy. The Committee qualitatively synthesized the body of evidence to inform development of conclusion statements, and graded the strength of evidence using pre-established criteria for risk of bias, consistency, directness, precision, and generalizability.

### Summary of the evidence

- Children
  - This systematic review includes 37 articles, 22 articles from 7 randomized controlled trials (RCTs) and 16 articles from 14 prospective cohort studies (PCSs), published between January 1990 and October 2019 that examined the relationship between intake of types of dietary fat during childhood and cardiovascular disease (CVD) risk. (Note: One article from an RCT was also analyzed as a PCS.)
    ○ The RCTs modified child fat intake either through dietary counseling that focused primarily on reducing saturated fatty acids (SFA) and dietary cholesterol intake, with additional encouragement to increase polyunsaturated fatty acid (PUFA) intake, or through provision of food products (i.e., eggs, extra virgin olive oil, or oily fish) that differed in types of fat including SFA, monounsaturated fatty acids (MUFA), PUFA, and/or dietary cholesterol.
    ○ The PCSs primarily assessed SFA or PUFA intake, with fewer studies on MUFA or dietary cholesterol intake; only two studies modeled replacement between different types of fat or macronutrients.
  - Most included studies assessed the relationship between intake of types of dietary fat during childhood and blood lipids.
    ○ Evidence from RCTs predominantly indicated that consuming less SFA and dietary cholesterol resulted in lower blood total cholesterol and low-density lipoprotein (LDL) cholesterol throughout childhood, particularly in boys; evidence from PCSs was consistent with the RCTs.
    ○ Although reduction of SFA intake was the primary focus of most RCTs, evidence from these RCTs also showed that higher PUFA intake resulted in decreased total blood cholesterol, particularly in boys; evidence from PCSs was broadly consistent with the RCTs.
    ○ Few studies, RCTs or PCSs, focused on the relationship between MUFA intake and blood lipids and the results were predominantly null.
    ○ The majority of studies assessed blood lipids during childhood; few assessed intake of types of fat during childhood and blood lipids into early adulthood.
  - Fewer studies assessed the relationship between intake of types of dietary fat during childhood and blood pressure.
    ○ It was difficult to discern the effect of consuming different types of fat in the RCT that contributed the most evidence due to additional advice to reduce sodium consumption.
    ○ Few PCSs were conducted on this topic and results were predominantly null.
  - Only one study included in this review assessed the relationship between intake of types of dietary fat during childhood and CVD endpoint outcomes and methodological limitations related to the dietary assessment confounded interpretation of results. Therefore, no conclusion could be drawn.
  - Limitations of this body of evidence:
    ○ Most articles did not report race and ethnicity, but those that did included predominantly White or Caucasian participants.
    ○ Some studies specifically recruited children with elevated or higher than average blood lipid levels, reducing generalizability.
    ○ RCTs had predominantly low risk of bias, but few pre-registered their analysis intentions and several RCTs did not provide information on allocation of randomization sequences.
    ○ Although many PCSs accounted for most or many key confounders, all PCSs did not account for at least one key confounder.
    ○ Approximately half of the diet assessment methods used in the PCSs were not validated; many PCSs had high attrition rates and did not provide information on those lost to follow-up.
- Adults
  - Adults: CVD intermediate outcomes
    - This systematic review includes 97 articles that examined the relationship between intake of types of dietary fat during adulthood and CVD intermediate outcomes, published between January 2010 and October 2019. Of these, 47 were from 47 parallel design RCTs, 46 were from 44 crossover design RCTs, and 5 were from non-randomized controlled trial designs. (Note: One parallel design RCT was also analyzed as a crossover design RCT.)
      ○ The articles examined intake of SFA, MUFA, PUFA, and dietary cholesterol.
      ○ The majority of articles specifically examined types of fat from different food sources, including food sources that are predominantly fat (e.g., butter and olive oil).
    - The relationship between types of dietary fat and blood lipids varied by the type of fat examined and the comparator.
      ○ [underlined: SFA intake:] Predominantly null effects were reported for SFA intake when replacement was not considered or when SFA was partially replaced by carbohydrates. However, among the studies that detected significant effects, all reported significantly higher total, LDL, and high-density lipoprotein (HDL) cholesterol with higher intake of SFA, compared to either lower intake of SFA or substitution with carbohydrate.
      ○ [underlined: Replacement of SFA with MUFA:] More than half of articles reported a beneficial effect of replacing a portion of SFA intake with MUFA intake on total and LDL cholesterol. Predominantly null effects were reported for HDL cholesterol and triglycerides.
      ○ [underlined: Replacement of SFA with PUFA:] More than half of articles reported a beneficial effect of replacing a portion of SFA intake with PUFA intake on total and LDL cholesterol. Predominantly null effects were reported for HDL cholesterol and triglycerides.
      ○ [underlined: MUFA intake:] Predominantly null effects were reported for MUFA intake when replacement was not considered or when MUFA was partially replaced with carbohydrates.
      ○ [underlined: Replacement of MUFA with PUFA:] Predominantly null effects were reported in articles that examined partial replacement of MUFA intake with PUFA intake.
        ■ Among the studies that found significant effects, the majority detected significantly lower levels of or significant decreases in total and LDL cholesterol when PUFA intake replaced a portion of MUFA intake.
        ■ Studies replacing a portion of MUFA intake with PUFA intake predominantly detected significant decreases or greater decreases in HDL cholesterol and significantly higher levels of, smaller decreases in, or greater increases in triglycerides.
      ○ [underlined: PUFA intake:] The vast majority of articles that assessed the effect of PUFA intake (without considering replacement) on total, LDL, or HDL cholesterol and triglycerides were null. However, among the few articles that detected significant effects, total and LDL cholesterol were significantly lower with greater PUFA intake, compared with lower PUFA intake; HDL cholesterol significantly increased or had smaller decreases with greater PUFA intake; and triglycerides were significantly lower or had greater decreases with greater PUFA intake.
    - Few articles published during the search years of the present review assessed the relationship between dietary cholesterol intake and blood lipids.
      ○ Predominantly null effects were reported for dietary cholesterol. However, among the few articles that found significant results, higher intake of dietary cholesterol, compared to lower intake, significantly increased or resulted in higher levels of total, LDL, and HDL cholesterol.
      ○ In several articles, it was not possible to isolate the independent effect of dietary cholesterol on blood lipids due to simultaneous changes in the total amount of fat or proportion of different types of fatty acids in the study diet.
    - Limitations of this body of evidence:
      ○ Several articles involved small sample sizes and lacked sufficient power.
      ○ Race or ethnicity was not consistently reported, but among those studies that provided this information, the majority included participants who were predominantly White or Caucasian.
      ○ It was not possible to isolate the independent effect of SFA, MUFA, or PUFA on blood lipids in several articles due to simultaneous changes of those three types of fat.
      ○ The majority of articles did not control for other dietary components beyond the intervention or test meal.
    - This systematic review builds and expands on the work of the 2015 Dietary Guidelines Advisory Committee, which answered the question “What is the relationship between intake of saturated fat and risk of cardiovascular disease?” and considered evidence from RCTs and PCSs from the 1960s to 2010.^iii^ This systematic review concurs with and updates the conclusions drawn by the 2015 Dietary Guidelines Advisory Committee.
  - Adults: CVD endpoint outcomes
    - This systematic review includes 94 articles that examined the relationship between intake of types of dietary fat during adulthood and CVD endpoint outcomes, published between January 2010 and October 2019. Of these, 90 were from 47 PCSs and 4 were from 3 nested case-control studies.
      ○ The articles primarily examined SFA, total PUFA, omega-3 (n-3) PUFA (including alpha-linolenic acid [ALA], eicosapentaenoic acid [EPA], docosahexaenoic acid [DHA], or docosapentaenoic acid [DPA]), or MUFA intake. Fewer articles examined omega-6 (n-6) PUFA (including linoleic acid [LA] or arachidonic acid [AA]) or dietary cholesterol intake.
      ○ Several articles modeled replacement between different types of fats or macronutrients or, in some cases, between different sources of the same type of fat. Few articles specifically assessed food sources that are predominantly fat (i.e., butter and olive oil) or types of fat from different food sources.
    - The relationship between types of dietary fat and CVD endpoint outcomes varied by the type of fat examined and the specific outcome assessed, with the most consistent results observed when replacement was modeled.
      ○ [underlined: Replacement of SFA with PUFA:] In this review, replacement of SFA with PUFA (predominantly total PUFA) in many studies was associated with significantly lower risk of CVD mortality and/or coronary heart disease (CHD) or associations were null. Fewer articles in this review reported data regarding the relationship between replacement of SFA with PUFA and other specific types of CVD including heart failure or stroke, and results were predominantly null.
      ○ [underlined: Replacement of SFA with carbohydrates:] In this review, replacement of SFA with carbohydrates and CVD outcomes were predominantly null. Most articles did not specify or differentiate between the types of carbohydrate replacing SFA (e.g., complex or simple carbohydrates/sugar).
      ○ [underlined: Replacement of SFA with MUFA:] In this review, predominantly null associations were observed between replacement of SFA with MUFA and total CVD and CHD. However, among the few articles that differentiated plant and animal sources, MUFA from plants tended to be associated with lower risk.
    - In addition to articles that reported on total PUFA intake, many specifically assessed n-3 PUFA and some assessed n-6 PUFA.
      ○ [underlined: Total n-3 PUFA:] Predominantly null or beneficial associations were observed between total n-3 PUFA intake and CVD outcomes.
      ○ [underlined: Types of n-3 PUFA:] When “long chain” n-3 PUFA (EPA, DHA, and sometimes DPA), primarily from marine sources, were assessed separately from ALA, more consistent associations with lower risk of CVD were observed.
      ○ [underlined: Total n-6 PUFA:] Associations between total n-6 PUFA intake and CVD were predominantly null.
      ○ [underlined: Types of n-6 PUFA:] In the few articles specifically assessing LA and AA separately, beneficial associations were more often observed for LA as compared to AA.
    - Few articles, with inconsistent results, assessed the independent relationship between dietary cholesterol intake and CVD endpoint outcomes, thereby further confounding meaningful conclusions. Due to the co-occurrence of dietary cholesterol and SFA in animal source foods, disentangling independent associations between dietary cholesterol and CVD endpoint outcomes in these observational studies is challenging.
    - Limitations of this body of evidence:
      ○ Many articles did not report race or ethnicity, but the majority of those that did involved participants who were predominantly White or Caucasian. Other important characteristics of participants in some included articles did not mirror those of the U.S. population, such as BMI and diet at baseline.
      ○ Although many articles accounted for the majority of key confounders, few accounted for all key confounders.
      ○ Some studies did not use validated dietary assessment methods or were limited by high attrition.
      ○ Although most studies included in this body of evidence were specifically designed to evaluate the relationship between diet and CVD, several articles were less direct as a result of being secondary analyses of RCTs or cohorts originally designed to assess outcomes other than CVD.
    - This systematic review builds upon the work of the 2015 Dietary Guidelines Advisory Committee, which answered the question “What is the relationship between intake of saturated fat and risk of cardiovascular disease?” and considered evidence from RCTs and PCSs from the 1960s to 2010.^iv^
      ○ Regarding the relationships between replacement of SFA with PUFA or carbohydrate, this systematic review concurs with and updates the conclusions drawn by the 2015 Dietary Guidelines Advisory Committee, providing additional context regarding specific CVD endpoint outcomes and the type of carbohydrate replacing SFA.
      ○ Regarding the relationship between replacement of SFA with MUFA, this systematic review concurs with and updates the conclusions drawn by the 2015 Dietary Guidelines Advisory Committee.

iii Dietary Guidelines Advisory Committee. 2015. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. U.S. Department of Agriculture, Agricultural Research Service, Washington, D.C.

iv Dietary Guidelines Advisory Committee. 2015. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. U.S. Department of Agriculture, Agricultural Research Service, Washington, D.C.

## FULL REVIEW

### Systematic review question

What is the relationship between types of dietary fat consumed and risk of cardiovascular disease?

### Conclusion statements and grades

#### Cardiovascular disease intermediate outcomes: Children

Strong evidence demonstrates that diets lower in saturated fatty acids and cholesterol during childhood result in lower levels of total blood and low-density lipoprotein cholesterol throughout childhood, particularly in boys. (Grade: Strong)

Moderate evidence indicates that diets higher in polyunsaturated fatty acids during childhood result in lower levels of total blood cholesterol throughout childhood, particularly in boys. (Grade: Moderate)

Insufficient evidence is available to determine the relationship between monounsaturated fatty acid intake during childhood and total blood and low-density lipoprotein cholesterol throughout childhood. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between intake of types of dietary fat during childhood and blood pressure throughout childhood. (Grade: Grade not assignable)

#### Cardiovascular disease endpoint outcomes: Children

Insufficient evidence is available to determine the relationship between intake of types of dietary fat during childhood and cardiovascular disease health outcomes during adulthood. (Grade: Grade not assignable)

#### Cardiovascular disease intermediate outcomes: Adults

Strong and consistent evidence from randomized controlled trials demonstrates that replacing saturated fatty acids with unsaturated fats, especially polyunsaturated fatty acids, in adults significantly reduces total and low-density lipoprotein cholesterol. Replacing saturated fatty acids with carbohydrates (sources not defined) also reduces total and low-density lipoprotein cholesterol, but significantly increases triglycerides and reduces high-density lipoprotein cholesterol. Since the 2015 Dietary Guidelines Advisory Committee review, evidence remains inadequate to differentiate among sources of carbohydrate and their impact on blood lipids. (Grade: Strong)

Insufficient evidence is available to determine an independent relationship between dietary cholesterol intake in adults and blood lipids, given the co-occurrence of cholesterol with saturated fats in foods. (Grade: Grade not assignable)

#### Cardiovascular disease endpoint outcomes: Adults

Strong evidence demonstrates that replacing saturated fatty acids with polyunsaturated fatty acids in adults reduces the risk of coronary heart disease events and cardiovascular disease mortality. (Grade: Strong)

Insufficient evidence is available to determine whether replacing saturated fatty acids with polyunsaturated fatty acids in adults affects the risk of stroke or heart failure. (Grade: Grade not assignable)

Insufficient evidence is available to determine whether replacing saturated fatty acids with different types of carbohydrates (e.g., complex, simple) in adults affects the risk of cardiovascular disease. (Grade: Grade not assignable)

Limited evidence is available regarding whether replacing saturated fatty acids with monounsaturated fatty acids in adults confers overall cardiovascular disease endpoint health benefits. Main sources of monounsaturated fatty acids in a typical American diet are animal fats, with co-occurrence of saturated fatty acids and monounsaturated fatty acids in these foods thereby obscuring the independent association of monounsaturated fatty acids with cardiovascular disease. Evidence reviewed from randomized controlled trials and prospective studies demonstrated benefits of plant sources of monounsaturated fats, including olive oil and nuts on cardiovascular disease risk. (Grade: Limited)

Moderate evidence indicates that total intake of omega-3 polyunsaturated fatty acids, particularly eicosapentaenoic acid and docosahexaenoic acid from food sources, by adults is associated with lower risk of cardiovascular disease. (Grade: Moderate)

Limited evidence suggests that intake of linoleic acid, but not arachidonic acid, during adulthood may be associated with lower risk of cardiovascular disease, including cardiovascular disease mortality. (Grade: Limited)

Insufficient evidence is available from randomized controlled trials to quantify an independent relationship between dietary cholesterol intake in adults and overall risk of cardiovascular disease. (Grade: Grade not assignable)

### Summary of the evidence

#### Children

- This systematic review includes 37 articles,^1–37^ 22 articles from 7 randomized controlled trials (RCTs) and 16 articles from 14 prospective cohort studies (PCSs), published between January 1990 and October 2019 that examined the relationship between intake of types of dietary fat during childhood and cardiovascular disease (CVD) risk. (Note: One article from an RCT was also analyzed as a PCS.)
  ○ The RCTs modified child fat intake either through dietary counseling that focused primarily on reducing saturated fatty acids (SFA) and dietary cholesterol intake, with additional encouragement to increase polyunsaturated fatty acid (PUFA) intake, or through provision of food products (i.e., eggs, extra virgin olive oil, or oily fish) that differed in types of fat including SFA, monounsaturated fatty acids (MUFA), PUFA, and/or dietary cholesterol.
  ○ The PCSs primarily assessed SFA or PUFA intake, with fewer studies on MUFA or dietary cholesterol intake; only two studies modeled replacement between different types of fat or macronutrients.
- Most included studies assessed the relationship between intake of types of dietary fat during childhood and blood lipids.
  ○ Evidence from RCTs predominantly indicated that consuming less SFA and dietary cholesterol resulted in lower blood total cholesterol and low-density lipoprotein (LDL) cholesterol throughout childhood, particularly in boys; evidence from PCSs was consistent with the RCTs.
  ○ Although reduction of SFA intake was the primary focus of most RCTs, evidence from these RCTs also showed that higher PUFA intake resulted in decreased total blood cholesterol, particularly in boys; evidence from PCSs was broadly consistent with the RCTs.
  ○ Few studies, RCTs or PCSs, focused on the relationship between MUFA intake and blood lipids and the results were predominantly null.
  ○ The majority of studies assessed blood lipids during childhood; few assessed intake of types of fat during childhood and blood lipids into early adulthood.
- Fewer studies assessed the relationship between intake of types of dietary fat during childhood and blood pressure.
  ○ It was difficult to discern the effect of consuming different types of fat in the RCT that contributed the most evidence due to additional advice to reduce sodium consumption.
  ○ Few PCSs were conducted on this topic and results were predominantly null.
- Only one study included in this review assessed the relationship between intake of types of dietary fat during childhood and CVD endpoint outcomes and methodological limitations related to the dietary assessment confounded interpretation of results. Therefore, no conclusion could be drawn.
- Limitations of this body of evidence:
  ○ Most articles did not report race and ethnicity, but those that did included predominantly White or Caucasian participants.
  ○ Some studies specifically recruited children with elevated or higher than average blood lipid levels, reducing generalizability.
  ○ RCTs had predominantly low risk of bias, but few pre-registered their analysis intentions and several RCTs did not provide information on allocation of randomization sequences.
  ○ Although many PCSs accounted for most or many key confounders, all PCSs did not account for at least one key confounder.
  ○ Approximately half of the diet assessment methods used in the PCSs were not validated; many PCSs had high attrition rates and did not provide information on those lost to follow-up.

#### Adults

##### Adults: CVD intermediate outcomes

- This systematic review includes 97 articles that examined the relationship between intake of types of dietary fat during adulthood and CVD intermediate outcomes, published between January 2010 and October 2019.^38–134^ Of these, 47 were from 47 parallel design RCTs, 46 were from 44 crossover design RCTs, and 5 were from non-randomized controlled trial designs. (Note: One parallel design RCT was also analyzed as a crossover design RCT.)
  ○ The articles examined intake of SFA, MUFA, PUFA, and dietary cholesterol.
  ○ The majority of articles specifically examined types of fat from different food sources, including food sources that are predominantly fat (e.g., butter and olive oil).
- The relationship between types of dietary fat and blood lipids varied by the type of fat examined and the comparator.
  ○ [underlined: SFA intake:] Predominantly null effects were reported for SFA intake when replacement was not considered or when SFA was partially replaced by carbohydrates. However, among the studies that detected significant effects, all reported significantly higher total, LDL, and high-density lipoprotein (HDL) cholesterol with higher intake of SFA, compared to either lower intake of SFA or substitution with carbohydrate.
  ○ [underlined: Replacement of SFA with MUFA:] More than half of articles reported a beneficial effect of replacing a portion of SFA intake with MUFA intake on total and LDL cholesterol. Predominantly null effects were reported for HDL cholesterol and triglycerides.
  ○ [underlined: Replacement of SFA with PUFA:] More than half of articles reported a beneficial effect of replacing a portion of SFA intake with PUFA intake on total and LDL cholesterol. Predominantly null effects were reported for HDL cholesterol and triglycerides.
  ○ [underlined: MUFA intake:] Predominantly null effects were reported for MUFA intake when replacement was not considered or when MUFA was partially replaced with carbohydrates.
  ○ [underlined: Replacement of MUFA with PUFA:] Predominantly null effects were reported in articles that examined partial replacement of MUFA intake with PUFA intake.
    ■ Among the studies that found significant effects, the majority detected significantly lower levels of or significant decreases in total and LDL cholesterol when PUFA intake replaced a portion of MUFA intake.
    ■ Studies replacing a portion of MUFA intake with PUFA intake predominantly detected significant decreases or greater decreases in HDL cholesterol and significantly higher levels of, smaller decreases in, or greater increases in triglycerides.
  ○ [underlined: PUFA intake:] The vast majority of articles that assessed the effect of PUFA intake (without considering replacement) on total, LDL, or HDL cholesterol and triglycerides were null. However, among the few articles that detected significant effects, total and LDL cholesterol were significantly lower with greater PUFA intake, compared with lower PUFA intake; HDL cholesterol significantly increased or had smaller decreases with greater PUFA intake; and triglycerides were significantly lower or had greater decreases with greater PUFA intake.
- Few articles published during the search years of the present review assessed the relationship between dietary cholesterol intake and blood lipids.
  ○ Predominantly null effects were reported for dietary cholesterol. However, among the few articles that found significant results, higher intake of dietary cholesterol, compared to lower intake, significantly increased or resulted in higher levels of total, LDL, and HDL cholesterol.
  ○ In several articles, it was not possible to isolate the independent effect of dietary cholesterol on blood lipids due to simultaneous changes in the total amount of fat or proportion of different types of fatty acids in the study diet.
- Limitations of this body of evidence:
  ○ Several articles involved small sample sizes and lacked sufficient power.
  ○ Race or ethnicity was not consistently reported, but among those studies that provided this information, the majority included participants who were predominantly White or Caucasian.
  ○ It was not possible to isolate the independent effect of SFA, MUFA, or PUFA on blood lipids in several articles due to simultaneous changes of those three types of fat.
  ○ The majority of articles did not control for other dietary components beyond the intervention or test meal.
- This systematic review builds and expands on the work of the 2015 Dietary Guidelines Advisory Committee, which answered the question “What is the relationship between intake of saturated fat and risk of cardiovascular disease?” and considered evidence from RCTs and PCSs from the 1960s to 2010.^v^ This systematic review concurs with and updates the conclusions drawn by the 2015 Dietary Guidelines Advisory Committee.

##### Adults: CVD endpoint outcomes

- This systematic review includes 94 articles that examined the relationship between intake of types of dietary fat during adulthood and CVD endpoint outcomes, published between January 2010 and October 2019.^135–228^ Of these, 90 were from 47 PCSs and 4 were from 3 nested case-control studies.
  ○ The articles primarily examined SFA, total PUFA, omega-3 (n-3) PUFA (including alpha-linolenic acid [ALA], eicosapentaenoic acid [EPA], docosahexaenoic acid [DHA], or docosapentaenoic acid [DPA]), or MUFA intake. Fewer articles examined omega-6 (n-6) PUFA (including linoleic acid [LA] or arachidonic acid [AA]) or dietary cholesterol intake.
  ○ Several articles modeled replacement between different types of fats or macronutrients or, in some cases, between different sources of the same type of fat. Few articles specifically assessed food sources that are predominantly fat (i.e., butter and olive oil) or types of fat from different food sources.
- The relationship between types of dietary fat and CVD endpoint outcomes varied by the type of fat examined and the specific outcome assessed, with the most consistent results observed when replacement was modeled.
  ○ [underlined: Replacement of SFA with PUFA:] In this review, replacement of SFA with PUFA (predominantly total PUFA) in many studies was associated with significantly lower risk of CVD mortality and/or coronary heart disease (CHD) or associations were null. Fewer articles in this review reported data regarding the relationship between replacement of SFA with PUFA and other specific types of CVD including heart failure or stroke, and results were predominantly null.
  ○ [underlined: Replacement of SFA with carbohydrates:] In this review, replacement of SFA with carbohydrates and CVD outcomes were predominantly null. Most articles did not specify or differentiate between the types of carbohydrate replacing SFA (e.g., complex or simple carbohydrates/sugar).
  ○ [underlined: Replacement of SFA with MUFA:] In this review, predominantly null associations were observed between replacement of SFA with MUFA and total CVD and CHD. However, among the few articles that differentiated plant and animal sources, MUFA from plants tended to be associated with lower risk.
- In addition to articles that reported on total PUFA intake, many specifically assessed n-3 PUFA and some assessed n-6 PUFA.
  ○ [underlined: Total n-3 PUFA:] Predominantly null or beneficial associations were observed between total n-3 PUFA intake and CVD outcomes.
  ○ [underlined: Types of n-3 PUFA:] When “long chain” n-3 PUFA (EPA, DHA, and sometimes DPA), primarily from marine sources, were assessed separately from ALA, more consistent associations with lower risk of CVD were observed.
  ○ [underlined: Total n-6 PUFA:] Associations between total n-6 PUFA intake and CVD were predominantly null.
  ○ [underlined: Types of n-6 PUFA:] In the few articles specifically assessing LA and AA separately, beneficial associations were more often observed for LA as compared to AA.
- Few articles, with inconsistent results, assessed the independent relationship between dietary cholesterol intake and CVD endpoint outcomes, thereby further confounding meaningful conclusions. Due to the co-occurrence of dietary cholesterol and SFA in animal source foods, disentangling independent associations between dietary cholesterol and CVD endpoint outcomes in these observational studies is challenging.
- Limitations of this body of evidence:
  ○ Many articles did not report race or ethnicity, but the majority of those that did involved participants who were predominantly White or Caucasian. Other important characteristics of participants in some included articles did not mirror those of the U.S. population, such as BMI and diet at baseline.
  ○ Although many articles accounted for the majority of key confounders, few accounted for all key confounders.
  ○ Some studies did not use validated dietary assessment methods or were limited by high attrition.
  ○ Although most studies included in this body of evidence were specifically designed to evaluate the relationship between diet and CVD, several articles were less direct as a result of being secondary analyses of RCTs or cohorts originally designed to assess outcomes other than CVD.
- This systematic review builds upon the work of the 2015 Dietary Guidelines Advisory Committee, which answered the question “What is the relationship between intake of saturated fat and risk of cardiovascular disease?” and considered evidence from RCTs and PCSs from the 1960s to 2010.^vi^
  ○ Regarding the relationships between replacement of SFA with PUFA or carbohydrate, this systematic review concurs with and updates the conclusions drawn by the 2015 Dietary Guidelines Advisory Committee, providing additional context regarding specific CVD endpoint outcomes and the type of carbohydrate replacing SFA.
  ○ Regarding the relationship between replacement of SFA with MUFA, this systematic review concurs with and updates the conclusions drawn by the 2015 Dietary Guidelines Advisory Committee.

### Description of the evidence: Children

Of the 228 articles that met inclusion criteria for this systematic review, 37 articles,^1–37^ 22 from 7 randomized controlled trials (RCTs) and 16 from 14 prospective cohort studies (PCSs), examined the relationship between types of dietary fat consumed during childhood and risk of cardiovascular disease (CVD). (Note: One article from an RCT also was analyzed as a PCS.)^32^

#### RCT Characteristics

Seventeen articles from 2 RCTs used dietary counseling to change intake of dietary fat.

In the Special Turku Coronary Risk Factor Intervention Project (STRIP; N=1,062 at baseline) conducted in Finland, 7-month-old infants were randomized to receive either counseling which encouraged adherence to a diet with a saturated fatty acid (SFA) to monounsaturated fatty acid (MUFA) to polyunsaturated fatty acid (PUFA) intake ratio of 1:1:1, dietary cholesterol intake of <200 mg per day, and total fat intake of 30-35% energy, or to basic health education counseling which recommended a PUFA:SFA intake ratio of 0.3-0.4.^8,10,11,14,15,21–24,28–31^ Counseling was delivered to the parents until children were age 7 years, after which, direct counseling to the children started to be incorporated STRIP assessed compliance via food diaries, which indicated that intervention children had consistently significantly lower SFA and dietary cholesterol intake and higher PUFA intake than control children. To date, follow-up and counseling for STRIP has continued through age 20 years.

In the Dietary Intervention Study in Children (DISC; N=663 at baseline) conducted in the U.S., children aged approximately 9.5 years with elevated LDL cholesterol were randomized to receive either counseling which encouraged adherence to a diet providing <8% of energy from SFA, up to 9% energy from PUFA, <75 mg per 1000 kilocalories of dietary cholesterol, and up to 28% energy from total fat, or to usual care.^6,13,25,32^ DISC assessed compliance via multiple 24 hour recalls; these indicated that intervention children had consistently lower SFA intake than control children and that during the first three years of the study MUFA and dietary cholesterol intake were also lower for intervention children. Counseling for DISC continued for approximately 7 years.

The remaining 5 articles from 5 RCTs, 1 parallel design, 3 crossover design, and 1 cluster design, provided children (predominantly age 9-12 years) with different food products to achieve differences in intake of types of dietary fat including SFA, MUFA, PUFA, and dietary cholesterol.^2,5,7,18,36^ These foods included oily fish (vs poultry),^36^ whole eggs (vs egg whites),^2^ products made with margarine (vs butter),^5^ whole milk (vs milk preparation),^7^ and extra-virgin olive oil (vs typical oil consumed).^18^ Sample size ranged from N=54^2^ to N=135.^18^ These RCTs were conducted in Denmark,^36^ Mexico, ^2^ Spain,^7,18^ and the U.S.^5^ In comparison to the RCTs that provided counseling, these 5 RCTs which provided food products were of shorter duration, with intervention durations ranging from 4 weeks^2^ to 7 months.^7^

Out of the 22 articles from RCTs, 20 reported on at least one blood lipid measurement (total cholesterol: 16; LDL cholesterol: 14; HDL cholesterol: 20; triglycerides: 16).^2,5–8,10,11,13–15,18,22–25,28–31,36^ Most blood draws were conducted in a fasted state, the primary exception being STRIP, which, due to the young age of the participants, collected non-fasting blood draws until the children were age 5 years. Only 10 articles reported on systolic and diastolic blood pressure.^2,6,8,15,18,21,24,28,32,36^ Most articles did not report race/ethnicity, a common practice in studies conducted in Europe. Of those studies that did report race/ethnicity, participants were predominantly White.^5,6,13,25,32^

#### PCS Characteristics

Of the 16 articles from 14 PCSs, 15 assessed intermediate outcomes^1,3,4,9,12,16,17,20,26,27,32–35,37^ and one assessed CVD endpoint outcomes.19 These studies were primarily conducted in the U.S.^1,27,32,37^ and the U.K.,^3,4,19,20^ with additional studies conducted in Australia,^16^ Brazil,^17^ Germany,^9^ Ireland,^12^ and the Netherlands.^26,33–35^ Sample size varied greatly, with 3 articles with N<100,^12,17,27^ 8 articles with N=100-1,000,^1,3,4,16,26,32,34,37^ and 5 articles with N>1000.^9,19,20,33,35^ Most PCSs did not report race/ethnicity of the participants, but among those that did, samples were predominantly White or Caucasian,^1,4,20,32,33,35^ except one study which reported greater diversity, with 40% of participants African American and 40% of participants Hispanic.^37^

Among studies that reported on intermediate outcomes, exposure assessment predominantly occurred during childhood and adolescence (approximately age 4-13 years). Dietary assessment methods varied across the PCSs that assessed intermediate outcomes. These methods, approximately half of which were validated, included food frequency questionnaires (FFQs), 24 hour recalls, multiple day diet records or diet diaries, diet history interviews, and direct observation. Most studies measured SFA^1,4,9,12,16,17,20,26,27,32–35,37^ or PUFA^1,4,9,12,20,26,27,32–35^ intake, with fewer measuring MUFA^1,4,9,12,20,32,33,35,37^ or dietary cholesterol^1,3,4,20,26,27,32,34^ intake. Only two studies examined replacement between types of fat or other macronutrients.^9,33^ Duration of follow-up for outcome assessment in these studies occurred primarily 1-5 years from baseline; however, several studies conducted follow-ups over a longer time period (approximately 15-20 years from baseline).^16,26,34^ The PCSs primarily assessed non-fasting blood lipids, with 13 reporting on at least one blood lipid measurement (total cholesterol: 10; LDL cholesterol: 6; HDL cholesterol: 11; triglycerides: 4).^1,3,4,9,12,16,17,20,26,27,33,34,37^ However, six of the PCSs assessed systolic and diastolic blood pressure.^3,17,26,32,35^

In the one study that examined CVD endpoint outcomes, follow-up lasted approximately 60 years, and stroke mortality and coronary heart disease (CHD) mortality were assessed.^19^ Initiated in the late 1930s in the U.K., this study estimated child SFA intake at approximately age 7.5 years using a 7-day weighed household inventory, dividing the total food expenditure for the child’s household by the total number of household members.^19^

### Evidence synthesis: Children

#### Intermediate outcomes

The RCTs on this topic primarily addressed multiple types of fat within single studies, considering replacement, whereas the PCSs predominantly examined types of fat separately, without addressing replacement. Therefore, for RCTs, the evidence was synthesized by the type of intervention (i.e., diet counseling or provision of food products) and outcome. For PCSs, the evidence was synthesized by type of fat and outcome. Evidence from RCTs and PCSs are described in Table 1 and Table 2, respectively. Risk of bias assessments from RCTs and PCSs are described in Table 3 and Table 4, respectively.

##### RCTs

Blood lipids. Twenty articles from 7 RCTs examined the relationship between intake of types of fat during childhood and blood lipids.^2,5–8,10,11,13–15,18,22–25,28–31,36^ Over half of these articles were from STRIP, unique in its early initiation of a dietary counseling intervention (beginning at age 7 months) and long duration of intervention and follow-up (approximately 19.5 years to date).^8,10,11,14,15,22–24,28–31^ In STRIP, a predominantly beneficial effect of the intervention, which reduced SFA and dietary cholesterol intake while increasing PUFA intake throughout childhood, was observed for total cholesterol,^8,10,11,14,15,22–24,28–31^ LDL cholesterol,^10,15,22,23,28,29^ and triglycerides^10,11,15,22–24,28,29^ in boys. Results were predominantly null for girls when analyzed separately from boys. HDL cholesterol was significantly lower in intervention group children, primarily girls, through age 5 years.^10,14,29–31^ However, from age 7 years and older no statistically significant differences between the intervention and control group children were detected for HDL cholesterol.^8,10,11,15,22–24,28^

Similar, but less sustained, results were observed in DISC for blood lipids.^6,13,25^ Children with LDL cholesterol levels at the 80^th^-98^th^ percentile at baseline who received the intervention in DISC (dietary counseling to primarily reduce SFA and dietary cholesterol, with less emphasis on replacement) had lower total cholesterol and LDL cholesterol at the 1- and 3-year follow-ups (conducted at approximately age 10.5 and 12.5 years, respectively) compared to the control group ^13^. However, no significant group differences were detected for total cholesterol or LDL cholesterol at the 5- and 7-year follow-ups (conducted at approximately 14.5 and approximately age 16.5 years, respectively) in the full cohort,^25^ or at the 16- to 20-year follow-up conducted exclusively in female participants.^6^ Triglycerides did not differ between groups at any time point, whereas HDL cholesterol was lower in the intervention group only at the 1-year follow-up.^6,13,25^ Given that DISC enrolled children with elevated LDL cholesterol at baseline, the generalizability of this particular cohort is reduced.

The five remaining RCTs that examined blood lipids were heterogeneous, all providing food products to change child fat intake, but each focusing on different foods and types of fats.^2,5,7,18,36^ One study increased long chain omega-3 (n-3) PUFAs (eicosapentaenoic acid [EPA] and docosahexaenoic acid [DHA]) by providing children with 300 grams per week of oily fish (compared to poultry with minimal long chain n-3 PUFA) for 12 weeks.^36^ Although no differences in LDL cholesterol were detected between groups, increased long chain n-3 PUFA intake increased total cholesterol and HDL cholesterol and decreased triglycerides compared to controls.^36^ Another study that focused on PUFAs, in addition to SFA and dietary cholesterol, compared consumption of 25% energy from margarine, as spreads or bakery products, to butter for five weeks in a crossover trial.^5^ Total cholesterol and LDL cholesterol were lower during the margarine period, which increased PUFA intake and decreased SFA and dietary cholesterol intake, compared to the butter period; no differences were detected between groups for HDL cholesterol or triglycerides.^5^ In another crossover study that addressed replacement of SFA with unsaturated fatty acids, children consumed either 500 mL per day of whole milk or a commercially available powdered milk lower in SFA and dietary cholesterol and higher in MUFA and PUFA for 7 months.^7^ Similar to the study comparing margarine to butter, total cholesterol and LDL cholesterol were lower following intake of the powdered milk higher in unsaturated fatty acids compared to intake of whole milk; no differences were detected for HDL cholesterol or triglycerides.^7^ One crossover study modulated dietary cholesterol intake, in addition to SFA and MUFA intake, by comparing intake of two whole eggs per day to an egg white substitute for 4 weeks.^2^ In this article, investigators categorized all participants as “hyper-” or “hyporesponders” to the dietary cholesterol intervention based on change in total blood cholesterol and this status was used as a variable in analyses.^2^ Intake of whole eggs significantly increased both LDL and HDL cholesterol compared to egg substitutes, but the effect was stronger in “hyperresponders”; no effect on triglycerides was detected.^2^ Finally, one cluster randomized study assessed replacement of typical oil consumed with extra virgin olive oil, which is rich in MUFAs.^18^ No significant effect of the intervention was detected on total, LDL, or HDL cholesterol, or triglycerides.^18^ However, because this study was conducted in Spain and refined olive oil would be the expected, predominant “typical oil consumed,” it is unlikely that the extra virgin olive oil increased MUFA intake at the expense of other types of fat in the intervention group.

Blood pressure. Ten articles from 5 RCTs examined the relationship between intake of types of fat during childhood and systolic or diastolic blood pressure.^2,6,8,15,18,21,24,28,32,36^ In STRIP, dietary counseling that reduced SFA and dietary cholesterol intake had a beneficial effect or no effect on systolic and diastolic blood pressure.^6,8,21,24,28,32^ However, the results for blood pressure in STRIP should be interpreted cautiously, as participants in the intervention group were also advised to reduce salt consumption as part of their counseling sessions.^6,8,21,24,28,32^ Therefore, it is difficult to discern the independent effect of changing intakes of types of fat on blood pressure in this cohort.^6,8,21,24,28,32^ In DISC, dietary counseling that targeted reduction of SFA intake, but not salt intake, had predominantly null effects on blood pressure.^6,32^ The remaining 3 RCTs, which modulated child fat intake through provision of different food products (i.e., oily fish, eggs, or extra virgin olive oil), found predominantly null results for systolic and diastolic blood pressure.^2,18,36^ In the study that compared intake of two whole eggs to egg substitutes for 4 weeks (modulating dietary cholesterol, SFA, and MUFA intake), a beneficial effect of the whole egg intervention was found for diastolic blood pressure, but not for systolic blood pressure.^2^ Neither the study on oily fish (to increase long chain n-3 PUFA intake) nor the study on extra virgin olive oil detected a significant effect on blood pressure.^18,36^ As noted previously, it is unlikely that the study on extra virgin olive oil provides a strong assessment of the effect of MUFA intake on blood pressure because the extra virgin olive oil likely replaced refined olive oil.^18^

##### PCSs

SFA and blood lipids. Twelve articles from 11 PCSs examined the relationship between SFA intake during childhood and blood lipids.^1,4,9,12,16,17,20,26,27,33,34,37^ Of these, nine assessed total cholesterol,^1,4,16,17,20,26,33,34,37^ six assessed LDL cholesterol,^4,9,16,17,27,33^ ten assessed HDL cholesterol,^4,9,12,16,17,20,26,33,34,37^ and four assessed triglycerides.^9,16,33,37^ Broadly consistent with RCTs, results were predominantly null^1,9,16,33,37^ or showed that higher intakes of SFA were associated with higher levels of total cholesterol^4,20,26,34^ or LDL cholesterol.^4,17,27^ Among the three studies that modeled replacement,^9,20,33^ only one detected statistically significant results, finding that replacement of SFA with carbohydrate intake was associated with higher LDL cholesterol in females, but not males;^9^ replacement of SFA with other types of fat in this study were non-significant.^9^ In the case of HDL cholesterol and triglycerides, the majority of studies reported null associations between SFA intake and these blood lipids.^4,9,12,16,20,33,34,37^ One study reported a statistically significant association between higher intake of SFA and higher HDL cholesterol,^26^ whereas one study reported statistically significant associations between higher intake of SFA and lower triglycerides and between replacement of SFA with carbohydrate intake and higher triglycerides.^9^

SFA and blood pressure. Five articles from 4 PCSs examined the relationship between SFA intake during childhood and blood pressure.^17,26,32,33,35^ The majority of these articles reported null associations between SFA intake and systolic or diastolic blood pressure,^17,26,32,33,35^ including the one study that modeled replacement.^33^ Only one study reported a statistically significant association between higher intakes of SFA at age 13 years and lower diastolic blood pressure at age 14 years.^26^

PUFA and blood lipids. Nine articles from 8 PCSs examined the relationship between PUFA intake during childhood and blood lipids.^1,4,9,12,20,26,27,33,34^ Of these, six assessed total cholesterol,^1,4,20,26,33,34^ four assessed LDL cholesterol,^4,9,27,33^ seven assessed HDL cholesterol,^4,9,12,20,26,33,34^ and two assessed triglycerides.^9,33^ Broadly consistent with the results of RCTs, the association between PUFA intake and total cholesterol was predominantly beneficial^4,26,34^ or null.^1,4,20,33^ Among the articles that reported on HDL cholesterol, the majority reported null associations with PUFA intake^9,20,26,33,34^; only one reported a beneficial association and this was observed only in girls.^4^ Of the few articles that assessed the relationship between PUFA intake and LDL cholesterol or triglycerides, including the three studies that examined replacement of other types of fat or macronutrients with PUFA, the majority of associations were null.^4,9,20,27,33^ Only one study reported a significant association between replacement of other types of fat with unsaturated fatty acids (i.e., MUFA and PUFA) and higher total cholesterol after two years of follow-up.^20^

PUFA and blood pressure. Four articles from 3 PCSs examined the relationship between PUFA intake during childhood and blood pressure.^26,32,33,35^ All articles reported null associations between PUFA intake and systolic or diastolic blood pressure,^26,32,33,35^ including the one study that modeled replacement of other types of fats or macronutrients with PUFAs.^33^

MUFA and blood lipids. Seven articles from 7 PCSs examined the relationship between MUFA intake during childhood and blood lipids.^1,4,9,12,20,33,37^ Of these, five assessed total cholesterol,^1,4,20,33,37^ three assessed LDL cholesterol,^4,9,33^ six assessed HDL cholesterol,^4,9,12,20,33,37^ and three assessed triglycerides.^9,33,37^ All associations between MUFA intake and blood lipids were non-significant,^1,4,9,12,20,33,37^ including studies that modeled replacement.^9,20,33^

MUFA and blood pressure. Three articles from 2 PCSs examined the relationship between MUFA intake during childhood and blood pressure.^32,33,35^ One of these studies detected a significant association between higher MUFA intake and higher diastolic blood pressure, but did not detect a significant association with systolic blood pressure.^32^ The other study reported null associations between MUFA intake and systolic or diastolic blood pressure,^33,35^ including when replacement of other types of fat or macronutrients was modeled.^33^

Dietary cholesterol and blood lipids. Seven articles from 6 PCSs examined the relationship between dietary cholesterol intake during childhood and blood lipids.^1,3,4,20,26,27,34^ Of these, six assessed total cholesterol,^1,3,4,20,26,34^ two assessed LDL cholesterol,^4,27^ five assessed HDL cholesterol,^3,4,20,26,34^ and none assessed triglycerides. Broadly consistent with RCTs, associations between dietary cholesterol and total blood cholesterol were detrimental^1,26,34^ or null.^1,3,4,20^ All associations between dietary cholesterol and HDL cholesterol were null^4,20,26,34^ except for one study that detected a significant association between higher dietary cholesterol and lower HDL cholesterol in girls, but not in boys.^3^ LDL cholesterol was not significantly associated with dietary cholesterol in either study that assessed this relationship.^4,27^ No study reported significant beneficial associations between dietary cholesterol and blood lipids.

Dietary cholesterol and blood pressure. Three articles from 3 PCSs examined the relationship between dietary cholesterol intake during childhood and blood pressure.^3,26,32^ All three studies reported null associations between intake of dietary cholesterol and systolic or diastolic blood pressure.^3,26,32^

PUFA to SFA ratio and blood lipids. Three articles from 3 PCSs examined the relationship between the PUFA:SFA intake ratio during childhood and blood lipids.^3,4,34^ Of these, all examined total cholesterol and HDL cholesterol,^3,4,34^ one examined LDL cholesterol,^4^ and none examined triglycerides. For total cholesterol, results were inconsistent with one study reporting a significant association between a higher PUFA:SFA intake ratio and lower total cholesterol,^34^ another reporting a significant association with higher total cholesterol (but only in boys),^4^ and the last reporting a null association.^3^ In the one study that assessed LDL cholesterol, a higher PUFA:SFA intake ratios was significantly associated with higher LDL cholesterol in boys, but not in girls.^4^ All three studies reported null associations between the PUFA:SFA intake ratio and HDL cholesterol.^3,4,34^

PUFA to SFA ratio and blood pressure. One article examined the relationship between the PUFA:SFA intake ratio during childhood and blood pressure.^3^ This study reported a null association between the PUFA:SFA intake ratio and systolic or diastolic blood pressure.^3^

#### CVD endpoint outcomes

One article studying the relationship between intake of types of fat during childhood and CVD endpoint outcomes in adulthood met inclusion criteria.^19^ Specifically, this prospective cohort study (N=4,028) assessed the association between SFA intake at approximately age 7.5 years and CHD mortality or stroke mortality during approximately 60 years of follow-up.^19^ In this cohort from the U.K., SFA intake was not significantly associated with either CHD mortality or stroke mortality. Results of this study were interpreted with caution due to serious limitations of the dietary assessment method. Specifically, child SFA intake was estimated by dividing total household intake, assessed with a 7-day weighed household inventory, by the number of household members. No information on the accuracy or validity of this assessment, conducted in the late 1930s, in regards to child intake was provided. Evidence and the risk of bias assessment for this study are described in Table 2 and Table 4, respectively.

#### Assessment of the evidence^vii^

As outlined and described below, the body of evidence examining intake of types of dietary fat during childhood and CVD intermediate and endpoint outcomes was assessed for the following elements used when grading the strength of evidence.

##### Risk of Bias

As noted previously, the risk of bias assessment for RCTs and PCSs are described in Table 3 and Table 4, respectively. The RCTs included in this portion of the review were generally of low risk of bias, with the exception of selection of the reported result for which most articles were assessed as having some concerns due to a lack of pre-registered statistical analysis plans or protocols. Information on the allocation of randomization sequences were not provided for the crossover and cluster RCTs.^2,5,7,18^ Risk of bias across the PCSs were predominantly low or moderate for several domains including selection of participants, deviations from intended exposures, and outcome measurement. All PCSs were at serious risk of bias due to confounding as none accounted for all key confounders. However, several studies did account for the majority of key confounders, including sex, age, race/ethnicity, and total energy intake. Over half of the PCSs were at moderate or serious risk of bias for classification of exposures due to the use of dietary assessment tools with no confirmation of validity. The majority of PCSs were also at moderate risk of bias for missing data due to high attrition rates without information on those lost to follow-up.

##### Consistency

The results from RCTs that modulated SFA, PUFA, and dietary cholesterol intake were predominantly consistent with one another, showing primarily beneficial effects throughout childhood for total cholesterol and LDL cholesterol. The PCSs that assessed SFA, PUFA, and/or dietary cholesterol intake were broadly consistent with these RCTs, showing primarily either statistically significant associations in the same direction as predicted by RCTs or null associations.

##### Directness

The majority of studies were designed to examine the relationship between dietary fat intake and risk of cardiovascular disease. However, the RCTs that provided dietary counseling were more directly focused on reduction of SFA and dietary cholesterol than changes in intake of MUFA or PUFA.

##### Precision

The majority of RCTs were powered to detect differences in blood lipids. Although sample size varied greatly across the PCSs, many had relatively large sample sizes.^3,9,19,20,32,33,35,37^

##### Generalizability

Most studies were conducted in the U.S., the U.K., and Scandinavia. Studies assessed dietary fat intake at a variety of ages during childhood, from infancy through adolescence. Many studies did not report race or ethnicity but those that did had samples that were predominantly White or Caucasian. The majority of studies included children with normal blood lipids at baseline, although some specifically recruited children with elevated or higher than average blood lipid levels.^6,13,25,27,32^

#### Other important considerations

A large, comprehensive search was conducted in multiple databases for this systematic review. Although risk of publication bias is always of potential concern, both small and large studies were included in this review, reporting both null and statistically significant results. Therefore, risk of publication bias is likely low across this body of evidence.

### Description of the evidence: Adults (Cardiovascular disease intermediate outcomes)

Of the 228 articles that met inclusion criteria for this systematic review, 97 articles examined the relationship between types of dietary fat consumed during adulthood and CVD intermediate outcomes (i.e., total cholesterol, LDL cholesterol, HDL cholesterol, and triglycerides). Of these, 47 articles were from 47 parallel design RCTs,^38,41,44,47–53,59,61,63–65,67,70,71,73–75,78,81,82,84,88,89,92,93,95,96,99,100,104,106,110,112,113,120,125–127,129,130,132–134^ 46 articles were from 44 crossover design RCTs,^39,42,43,45,46,49,54–58,60,62,66,68,69,72,76,77,79,80,83,85–87,90,91,94,97,98,101–103,105,107–109,111,115,118,119,121,122,124,128,131^ 4 articles were from 4 crossover design non-randomized controlled trials (NRCT),^40,114,116,117^ and 1 article was from a parallel design NRCT.^123^ (Note: One parallel design RCT was also analyzed as a crossover design RCT.)^49^ Except for four articles from two crossover design RCTs,^83,91,94,111^ all articles reported on unique trials.

Detailed information on sample characteristics, intervention, comparator, including the distribution of types of fats in the intervention/comparator and dietary intake are described in Table 5. Sample sizes varied across articles, ranging from N=9^103^ to N=164^91,111^ for crossover designs and from N=17^129^ to N=1,204^81^ for parallel designs; the majority of articles had sample sizes of 100 participants or less. Participants were predominantly middle-aged or older adults with overweight or obesity and with normal blood lipids levels or mild hyperlipidemia. However, several studies specifically recruited participants at elevated risk for CVD, such as individuals with metabolic syndrome^41,47,52,70,71,77,100,108,134^ or multiple components of metabolic syndrome,^44,54,82,83,86,94,99,110^ overweight or obese with one or more component of metabolic syndrome,^43,44,53,66,77,103,107^ high blood pressure,^91,111^ prediabetes,^107^ polycystic ovary syndrome,^84^ or who survived breast cancer.^123^ Fourteen articles reported on studies that were conducted in younger adults, with mean ages less than 30 years^51,57,58,61,64,67,78,85,90,96,101,114,122,133^; these participants tended to have fewer risk factors for CVD and were predominantly of normal body mass index (BMI). Approximately 40% of the included studies were conducted in the U.S.; however, varieties of countries were represented across the body of evidence. These countries included:

- Australia^46,65,73,93,118,120^
- Brazil^63,71^
- Canada^39,42,54,55,66,83,94^
- China^57,96,119^
- Colombia^95^
- Denmark^51,68,75,110,132^
- Finland^81,108^
- France^134^
- Germany^47,62,67,92^
- Greece^90^
- Iran^41,70^
- Ireland^134^
- Italy^44,79,116,117^
- Japan^87^
- Malaysia^85,104,121,122^
- Netherlands^53,99,109,127,128,134^
- Norway^74,130,134^
- Poland^134^
- Spain^102,105,134^
- Sweden^50,78,134^
- Thailand^58^
- Turkey^114^
- U.K.^80,82,88,126,134^
- U.S.^38,40,43,45,48,49,52,54,56,59–61,64,69,72,76,77,83,84,86,89,91,94,97,98,100,101,103,106,107,111–113,115,123–125,129,131,133^

The type or types of dietary fat focused upon varied across the articles included in this body of evidence. Articles focused on a single type of fat, modulated multiple types of fat, or both. Of the articles that examined a single type of fat, 12 articles primarily examined SFA,^48,49,55,58,66,88,97,104,116,121,125,132^ 12 articles primarily examined MUFA,^38,43,45,46,63,64,91,103,107,111,131^ 11 articles primarily examined PUFA.^41,44,47,56,62,73,86,87,97,106,117^ Additionally, 9 articles primarily addressed dietary cholesterol as the exposure,^42,52,56,61,80,101,113,115,127^ although other types of fat often were not controlled for and varied between groups in these articles. Most articles modulated multiple types of dietary fat, such as by replacing one type of fat with another or by changing the proportions of multiple types of fat in relation to other macronutrients. Of these articles that modulated multiple types of dietary fat, 29 focused on SFA and MUFA,^39,40,49,51,53–55,57,59,68,72,76,79,81,82,88,95,96,98,99,102,105,108,118,119,122,126,134^ 10 focused on SFA and PUFA,^50,55,65,71,78,79,81,96,102,126^ 17 focused on MUFA and PUFA,^54,70,83–85,90,92,94,96,100,102,109,112,114,120,124,126^ and 15 focused on SFA, MUFA, and PUFA.^60,67,69,74,75,77,89,93,110,117,123,128–130,133^

In most articles, dietary fat intake was manipulated by providing test foods varying in fatty acid content to participants. The majority of the test foods were provided in their natural form; few studies provided specially formulated oils that are not widely available or consumed by the public. Approximately one-third of articles reported on controlled feeding trials in which study investigators provided all food to be consumed during the study period to participants.^43–45,51,53,55,57,67,82,83,85,89,91,96,98,99,106,111,118,119,121–124,129,131,133^ In both cases, the majority of studies provided the test foods or meals daily. Most articles specified the primary food source of the dietary fat under study. These foods included oil (e.g., coconut oil, olive oil, and rapeseed oil),^41,43,47,50,53–55,57,58,62,67,68,70,76,78,82,83,85,87,88,90,92,94–96,99,100,102,104,108,109,112,118,119,121,122,126,131^ butter^50,55,65,68,71,88,102,108,112,125,126,132^ and other dairy products,^39,48,49,59,66,79,105,110,116,125,128^ nuts,^38,43,45,46,56,63–65,84,86,98,107,114,124^ eggs,^42,52,56,61,101,113,115,127^ meat,^40,49,60,72–75,97,106^ and fish.^44,73–75,80,106,117^ Few articles did not report information on the primary food source of the dietary fat under study.^51,69,77,81,89,91,93,103,111,120,123,129,130,133,134^ Several studies were designed to induce weight gain,^78^ maintain weight loss,^51^ or induce weight loss in participants during the intervention trial.^89,93,120,129^ Intervention durations ranged from 4 weeks (the minimum required for inclusion in this review) to 19.5 years in parents of STRIP participants^81^; however, most interventions were 4 to 8 weeks in duration, with crossover design trials tending to have shorter intervention periods than parallel design trials. Among crossover trials, the duration of washout periods ranged from 1 week^45,122^ to 10 weeks.^62,116^ A washout period was not reported in three studies,^46,69,114^ two of which had intervention arm durations of only 4 weeks. Although the majority of studies measured compliance using food diaries or FFQs, 30 out of 97 studies did not report compliance to the dietary intervention.

All articles assessed fasting blood lipids as the outcome. The majority of studies examined total blood cholesterol, LDL cholesterol, HDL cholesterol, and triglycerides. However, a few trials did not examine total blood cholesterol^40,77,96,112^ or HDL cholesterol.^51^

### Evidence synthesis: Adults (Cardiovascular disease intermediate outcomes)

Evidence was synthesized by type of fat. Evidence from RCTs and NRCTs are described in Table 5. The risk of bias assessments are described in Table 6 (for RCTs) and Table 7 (for NRCTs).

#### SFA

Twelve articles (6 from parallel design RCTs, 6 from crossover design RCTs) assessed the relationship between consumption of SFA, compared to either different types, amounts or sources of SFA or replacing a portion of SFA with carbohydrate, during adulthood and blood lipid levels.^48,49,55,58,66,88,97,104,116,121,125,132^ (Note: One article reported on a study that was analyzed as both a parallel design and crossover design RCT.)^49^ Across different amounts, types and sources of SFA, results were predominantly null for blood lipids.^48,49,55,58,66,88,97,104,116,121,132^ However, the consistency and pattern of results varied by the type of blood lipid and comparator. Among articles that did detect statistically significant effects on total and LDL cholesterol, most reported significantly higher levels of total or LDL cholesterol with higher intake of SFA, compared to either lower amounts of SFA or substitution with carbohydrate.^55,66,125^ Among the few articles that did detect statistically significant effects on HDL cholesterol, SFA intake, primarily replacing a portion of carbohydrates, resulted in significantly higher levels of HDL cholesterol.^55,58,121,125^ The vast majority of articles that assessed effect of SFA intake on triglycerides were null. When examining different sources of SFA, SFA from butter^88^ or red or white meat^49^ significantly increased total or LDL cholesterol compared to SFA from tropical oils, whereas SFA from coconut oil^88^ or red or white meat^49^ significantly increased HDL cholesterol compared to SFA from butter and tropical oils, respectively. The one study that examined the effect of different types of SFA (palmitic vs stearic acids) did not find an effect on total, LDL, or HDL cholesterol, but reported a significant greater levels of triglycerides with palmitic acid.^104^

#### Replacement of SFA with MUFA

Twenty-nine articles (12 from parallel design RCTs, 16 from crossover design RCTs, and 1 NRCT) assessed the relationship between MUFA intake replacing a portion of SFA during adulthood and blood lipid levels.^39,40,49,51,53–55,57,59,68,72,76,79,81,82,88,95,96,98,99,102,105,108,118,119,122,126,134^ The consistency and pattern of results varied by outcome. Over half of articles reported a statistically significant effect of MUFA intake replacing a portion of SFA on total and LDL cholesterol, most of which reported a beneficial effect of MUFA on total cholesterol and LDL cholesterol,^39,49,53–55,68,76,81,82,88,95,98,102,108,121,122,126^ and only one article finding higher LDL cholesterol when SFA was replaced with MUFA.^96^ Among articles that examined the effect of replacing SFA intake with MUFA intake, the vast majority detected no effect on HDL cholesterol.^39,49,53–55,57,59,68,81,82,88,95,96,98,99,102,105,108,118,119,121,126,134^ Those articles that did detect significant effects were mixed, some finding higher HDL cholesterol with higher MUFA intake,^40,72,122^ but others finding higher HDL cholesterol with higher SFA intake.^76,88^ Compared to other blood lipids, fewer articles detected a significant effect of MUFA intake on triglycerides. As with HDL cholesterol, the effects of MUFA intake replacing a portion of SFA on triglycerides were predominantly null.^39,49,51,53–55,59,68,72,76,79,81,82,88,95,96,98,99,102,105,108,118,119,121,126,134^ Among the articles that detected a significant effect, all studies reported lower triglycerides or greater decreases in triglycerides with MUFA intake replacing a portion of SFA intake.^40,57,99,122^

#### Replacement of SFA with PUFA

Ten articles (7 from parallel design RCTs, 3 from crossover design RCTs) assessed the relationship between PUFA intake replacing a portion of SFA during adulthood and blood lipid levels.^50,55,65,71,78,79,81,96,102,126^ The consistency and pattern of results varied by outcome. Over half of articles reported a statistically significant effect of PUFA intake replacing a portion of SFA on total and LDL cholesterol, all of which reported a beneficial effect of PUFA on total cholesterol or LDL cholesterol.^50,55,81,96,102,126^ All articles reported null effects of PUFA intake replacing a portion of SFA on HDL cholesterol.^50,55,65,71,78,79,81,96,102,126^ The vast majority of articles that assessed effect of SFA intake on triglycerides were null, with only one study reporting a significantly higher levels of triglycerides after SFA consumption compared to PUFA intake.^55^

#### MUFA

Fourteen articles (5 from parallel design RCTs, 9 from crossover design RCTs) assessed the relationship between MUFA intake, compared to either different amounts or sources of MUFA or replacing a portion of MUFA with carbohydrate, during adulthood and blood lipid levels.^38,43,45,46,63,64,91,103,107,111,131^ Across different amounts, types and sources of MUFA, results were predominantly null.^38,43,45,46,51,63,64,82,91,103,107,111,131^ However, the consistency and pattern of results varied by the type of blood lipids and dietary comparator. Among the few articles that detected a statistically significant effect on total and LDL cholesterol, MUFA intake, primarily replacing a portion of carbohydrates, resulted in significantly lower levels or had greater decreases in total or LDL cholesterol.^111,131^ Among the few articles that detected a statistically significant effect on HDL cholesterol, all but one article reported that MUFA intake, primarily replacing a portion of carbohydrates, resulted in significantly higher levels or a smaller decrease in HDL cholesterol.^64,111,131^ Similar to total and LDL cholesterol, the vast majority of articles that assessed the effect of MUFA intake on triglycerides were null. Only two studies reported significant effects, both of which reported greater decreases in triglycerides with higher MUFA intake.^111,131^ Regarding source of MUFA, only one study maintained MUFA intake constant but varied the source of MUFA.^131^ This article reported significantly greater decreases in total and LDL cholesterol after consumption of MUFA from avocado, compared to MUFA from sunflower and canola oil.^131^

#### Replacement of MUFA with PUFA

Eighteen articles (10 from parallel design RCTs, 7 from crossover design RCTs, 1 NRCT) assessed the relationship between PUFA intake replacing a portion of MUFA during adulthood and blood lipids.^47,54,70,83–85,90,92,94,96,100,102,109,112,114,120,124,126^ Across different amounts, types and sources of PUFA, results were predominantly null for blood lipids.^47,54,70,83–85,90,92,94,96,100,102,109,112,114,120,124,126^ However, the consistency and pattern of results of studies that detected significant effects varied by the type of blood lipid. Several articles detected a statistically significant effect on total and LDL cholesterol, the majority reporting that higher intake of PUFA replacing a portion of MUFA resulted in significantly lower levels of or significant decreases in total or LDL cholesterol.^83,94,96,120^ The remaining articles reported significantly lower levels of or decrease in total or LDL cholesterol with higher intake of MUFA replacing a portion of PUFA.^70,114^ Among the few articles that detected a statistically significant effect on HDL cholesterol, all articles reported that PUFA intake replacing a portion of MUFA, resulted in significant decreases or greater decreases in HDL cholesterol.^70,83,85,94^ Similar to total, LDL, and HDL cholesterol, the vast majority of articles that assessed the effect of PUFA intake replacing a portion of MUFA on triglycerides were null. Among the few articles that detected a statistically significant effect on triglycerides, majority of articles reported that PUFA intake replacing a portion of MUFA, resulted in significantly higher levels of, smaller decreases in, or greater increases in triglycerides.^70,83,85,94^ Only one article reported a greater decrease with PUFA intake replacing a portion of MUFA.^47^ Additionally, two articles from the COMIT I trial reported a beneficial change in HDL cholesterol or triglycerides with either higher MUFA or PUFA depending on the type of oil compared.^83,94^

#### PUFA

Ten articles (4 from parallel design RCTs, 5 from crossover design RCTs, 1 NRCT) assessed the relationship between PUFA intake, compared to either different amounts or sources of PUFA or replacing a portion of PUFA with carbohydrate, during adulthood and blood lipids.^41,44,56,62,73,86,87,97,106,117^ Across different amounts, types and sources of PUFA results were predominantly null.^41,44,47,56,62,73,86,87,97,106,117^ The vast majority of articles that assessed the effect of PUFA intake on total and LDL cholesterol were null.^41,44,56,62,73,86,97,106,117^ Among the few articles that detected a statistically significant effect of amount of PUFA on HDL cholesterol, both studies reported either significantly higher levels of or smaller decreases in HDL cholesterol with greater PUFA intake.^62,106^ Among the few articles that detected statistically significant effects of PUFA on triglycerides, all studies reported a significantly greater decrease or lower levels of triglycerides with greater PUFA intake.^56,62,106^ When comparing types of PUFA (alpha-linolenic acid [ALA] vs linoleic acid [LA]), one study reported significantly higher total, LDL, and HDL cholesterol with higher ALA intake in a study conducted only in men.^87^

#### SFA, MUFA, and PUFA

The following articles were weighed less heavily in the synthesis due to weaknesses in the study design. In fifteen articles, it was not possible to isolate the independent effect of SFA, MUFA or PUFA on blood lipids due to simultaneous changes of those three types of fat.^60,67,69,74,75,77,89,93,110,117,123,128–130,133^ Results of these articles were predominantly null.^60,67,69,74,75,77,89,93,110,117,123,128,129,133^ Among these studies, five concurrently restricted the energy composition of the intervention and/or control diet, making it difficult to detect the independent effect of dietary fat modification.^89,93,123,129,130^ In a study designed to maintain recent weight loss, participants in all intervention arms experienced significant weight gain during the intervention, potentially obscuring results related to fat modification.^51^ However, among the studies that found significant effects, higher-fat diets, higher in all types of fat, tended to increase LDL and HDL cholesterol,^74,77^ and lower-fat diets (typically higher in carbohydrates) tended to increase triglycerides.^69,77,123^ There were mixed findings for total cholesterol, with one study^67^ reporting significantly greater increases in total cholesterol with higher-fat diet and another reporting significantly greater decreases in total cholesterol with a higher-fat diet.^130^

#### Dietary cholesterol

Nine articles (4 from parallel design RCTs and 5 from crossover design RCTs) primarily assessed the relationship between dietary cholesterol intake and blood lipids.^42,52,56,61,80,101,113,115,127^ Of these, most achieved differences in dietary cholesterol intake by providing the intervention arm with meals or beverages that contained whole eggs or egg yolks and the comparator arm with dietary cholesterol-free alternatives such as egg substitutes, egg whites, or carbohydrate based breakfast foods (e.g., oatmeal).^42,52,56,61,101,113,115,127^ However, in one article the source of dietary cholesterol was prawns, which also provided 0.6-0.7 grams of EPA and DHA.^80^ Across the body of evidence, higher dietary cholesterol intake, compared to lower dietary cholesterol intake, had either null effects on blood lipids,^52,56,61,80,113,115,127^ or increased or resulted in higher levels of total blood cholesterol,^42,56,101^ LDL cholesterol,^42,101^ HDL cholesterol,^42,101^ and/or triglycerides.^56^ One article, which compared consumption of standard or n-3 PUFA enriched eggs to walnuts (free of dietary cholesterol), reported mixed results that varied by the type of egg.^56^ When intake of standard eggs was compared to walnuts, higher dietary cholesterol increased total blood cholesterol and triglycerides, whereas when intake of n-3 PUFA enriched eggs was compared to walnuts, no effect on blood lipids was detected.^56^ In several articles, it was not possible to isolate the independent effect of dietary cholesterol on blood lipids due to between-group differences in total fat intake,^101,113^ SFA intake,^101,113^ MUFA intake,^101,127^ or PUFA intake^56,80^ also attributable to the intervention and comparator foods. Additionally, some articles did not report the fat content of the intervention and comparator foods.^42,52^ Therefore, it was difficult to evaluate the independent effect of dietary cholesterol on blood lipids across this body of evidence.

#### Assessment of the evidence^viii^

As outlined and described below, the body of evidence examining intake of types of dietary fat by adults and CVD intermediate outcomes was assessed for the following elements used when grading the strength of evidence.

##### Risk of Bias

As noted previously, the risk of bias assessment for RCTs and NRCTs are described in Table 6 and Table 7, respectively. All RCTs were assessed as having low risk of bias for outcome measurement and over half were assessed as having low risk of bias for missing outcome data and deviations from intended interventions. In contrast, there were some concerns regarding selection of the reported result for the majority of articles from RCTs, as few articles reported a pre-registered protocol with sufficient information to assess statistical analysis intentions. Over half of the articles from RCTs had some concerns regarding randomization, as many did not provide information on the randomization and concealment of the allocation sequence. Among the few NRCTs, risk of bias was primarily assessed as low; however, all articles were assessed as being at serious risk of bias for confounding and at moderate risk of bias for selection of reported result.

##### Consistency

Consistency in results was observed across the body of evidence. Although the relationship between types of dietary fat and blood lipids varied by the type of fat examined, replacing macronutrient or other types of fat, or the specific blood lipid, significant effects within those categories tended to be in the same direction.

##### Directness

Although many studies in this body of evidence were specifically designed to evaluate the relationship between types of dietary fat and blood lipids, others were less direct due to the nature of the intervention. For example, many articles were primarily interested on the effect of foods rich in particular types of fat, such as dairy, nuts, or fish, on blood lipids. Because these foods commonly produced differences in intake of multiple macronutrients and/or multiple types of fat, it was sometimes difficult to assess precisely the relationship between types of dietary fat and blood lipids. Less frequently, studies were primarily interested in assessing the effect of replacing total fat with carbohydrates, reducing intake of all types of fat but primarily from SFA. Again, this made it difficult to attribute effects or lack of effects specifically to a single type of fat versus multiple types of fat or a total reduction in fat intake.

##### Precision

Fewer than half of included articles reported a power calculation specific to blood lipids. Of these articles, most reported having adequate power. The remaining articles did not report a power analysis or had calculated the power of the trial for an alternative outcome. Many of these studies had particularly small sample sizes, so the precision of these articles may not be strong.

##### Generalizability

Most articles reported on studies conducted in the U.S. (over one-third of articles), and in a variety of countries across Europe. Race and ethnicity were not commonly reported in this body of evidence. Most articles that did report race and ethnicity had participants who were predominantly White or Caucasian. Although participants were predominantly middle-aged or older adults with overweight or obesity and with normal blood lipid levels or mild hyperlipidemia, studies were conducted in a variety of populations such as younger adults with low risk of CVD or middle-aged adults at elevated risk of CVD (e.g., individuals with metabolic syndrome).

#### Other important considerations

##### Publication bias

A large, comprehensive search was conducted in multiple databases for this systematic review. Although risk of publication bias is always of potential concern, this body of evidence was composed primarily of small and moderately sized studies that reported both null and statistically significant results. Therefore, the risk of publication bias is likely low across this body of evidence.

##### Building on the 2015 Dietary Guidelines Advisory Committee report and conclusions

This systematic review builds and expands on the work of the 2015 Dietary Guidelines Advisory Committee, which answered the question, “What is the relationship between intake of saturated fat and risk of cardiovascular disease?” and considered evidence from systematic reviews and meta-analyses, which included RCTs and PCSs from the 1960s to 2010.^ix^ The 2015 Committee drew one conclusion pertaining to intermediate CVD outcomes (i.e., blood lipids):

- “Strong and consistent evidence from RCTs shows that replacing SFA with unsaturated fats, especially PUFA, significantly reduces total and LDL cholesterol. Replacing SFA with carbohydrates (sources not defined) also reduces total and LDL cholesterol, but significantly increases triglycerides and reduces HDL cholesterol. (Grade: Strong)”

The evidence in the present review is broadly consistent with this conclusion drawn by the 2015 Committee. In articles that examined replacement of SFA with MUFA or PUFA, MUFA or PUFA intake replacing a portion of SFA intake predominantly showed lower levels of or larger decreases in total blood and LDL cholesterol or null effects. Relative to articles that looked at replacement of SFA with unsaturated fatty acids, few articles in this body of evidence examined the effect of replacing SFA with carbohydrates. Across these articles, results were null or showed effects consistent with conclusions from the 2015 Committee, mainly lower total blood, LDL, and HDL cholesterol when SFA was replaced with carbohydrates. Based on the evidence in the present review, the 2020 Committee concurred with and updated the conclusions drawn by the 2015 Committee regarding replacement of SFA with MUFA, PUFA, or carbohydrates, with edits to increase the specificity of the conclusions.

### Description of the evidence: Adults (Cardiovascular disease endpoint outcomes)

Of the 228 articles that met inclusion criteria for this systematic review, 94 articles examined the relationship between intake of types of dietary fat and CVD endpoint outcomes in adults. Of these, 90 articles were PCS designs (47 cohorts)^135–171,173–188,190–194,196–208,210–228^ and 4 articles were nested case-control (NCC) designs (3 cohorts).^172,189,195,209^ Sample sizes across the PCSs varied greatly, ranging from N=495^176^ to N=521,120,^226^ although most studies had >10,000 participants. The NCC studies had relatively smaller sample sizes, ranging in size from n=97 cases and n=194 controls^195^ to n=720 cases and n=1,568 controls.^172^ Participants were predominantly healthy middle-aged or older adults with overweight and without CVD at baseline. Almost half of studies also excluded individuals with prevalent cancer or diabetes. Although two studies only recruited individuals at high risk for CVD,^163,164,184,202^ the majority of studies recruited from the population more generally. Most articles excluded participants with prevalent CVD, but some did not.^136,139,142,147,152,173^ Most studies were conducted in cohorts that included both men and women, although some studies enrolled only men^135,139,144,166,174,176,205,213,214,219^ or only women.^140,141,143,145–147,152,179,181,182,194,200,208,220^ Race or ethnicity was not consistently reported, particularly in studies conducted in Europe. Among studies that did report race or ethnicity, participants were predominantly White or Caucasian.

However, several cohorts from the U.S. reported more diverse samples.^156,157,161,168,173,201,224,225^ Most studies were conducted in the U.S. and Scandinavia. Varieties of other countries were represented across the body of evidence, however. Countries represented in the body of evidence included:

- Australia^147,191,192^
- Czech Republic^207^
- Denmark^148,149,160,170,171,198,208,210–212^
- Finland^135,176,205,213,214^
- France^203^
- Greece^177^
- Italy^143,193,195^
- Japan^166,185–187,190,216,221,222^
- The Netherlands^153–155,162,196,197,215^
- Norway^169^
- Poland^207^
- Russia^207^
- Singapore^175,188,189,209^
- Spain^138,150,151,163,164,202,204^
- Sweden^137,144–146,158,165,167,174,178,179,181,182,194,206,217^
- U.K.^136,139,198^
- U.S.^140–142,152,156,157,159,161,168,172,173,180,183,184,199–201,218–220,223–228^

The majority of studies measured dietary fat intake with validated FFQs, administered once at baseline. However, 11 articles assessed dietary fat intake multiple times with validated FFQs.^139,152,163,164,180,183,202,218,223,227,228^ Other dietary assessment methods reported in these studies included 24-hour recalls,^190,201,225^ food diaries/diet records,^135,176,184,213,214^ and weighed individual or household food records.^166,185,187,210^ Of the 94 included articles, 39 assessed SFA intake,^136,139,140,147,152,156,161,163,167,168,170,178,179,183,186–188,190,191,195–199,201,204,205,212,213,215–218,220–222,226–228^ 29 assessed MUFA intake,^139,152,161,163,168,179,183,186,188,190,195–199,201,204,205,212,213,215–218,220,222,226–228^ 71 assessed PUFA intake (including total PUFA intake, n-3 PUFA intake, and/or omega-6 [n-6] PUFA intake),^136–142,144–146,148,149,152–155,157–160,163,165–169,171–175,178–183,185–190,192,195–202,204,205,208–213,215–220,222,223,225,226,228^ and 11 assessed dietary cholesterol intake.^135,140,168,179,184,187,188,195,214,220,224^ Several of these studies modeled replacement between different types of fats or macronutrients, or in some cases between different sources of the same type of fat.^152,156,163,170,196–198,201,204,205,212,213,215,218,222,226–228^ Few articles specifically assessed types of fat from different food sources.^155,156,163,169,196–198,215,226,227^ Furthermore, because the literature search predominantly focused on types of fat, and not food sources that contain fat, few articles directly assessed common food sources of fat, including butter (predominantly SFA)^162,176,193,194,206^ and olive oil (predominantly MUFA).^143,150,151,164,177,203,207^

CVD endpoint outcomes were assessed primarily through linkage to national registries for hospital discharges, medical records, and cause of death, although in some cases presence of the outcome was also assessed through follow-up directly with participant or next of kin. Average time of follow-up ranged from approximately 5 years^142,147,164,191,195^ to approximately 30 years,^152,218^ but most studies had an average follow-up of at least 10 years. Of the included studies, 41 articles reported on incident CVD, inclusive of multiple types of fatal and/or nonfatal cases or events including myocardial infarction (MI), CHD, and stroke, of which 28 assessed CVD mortality alone^136,142,150,158,159,161,163,164,166,173,175,185,186,188,192,193,199–202,207,216,218,222–226^ and 18 assessed nonfatal cases or events or a combination of fatal and nonfatal cases or events.^140,156,157,163–165,167,168,177,184,191,200,204,206,208,217,221,224^ Additionally, articles reported on more specific categories of CVD endpoint outcomes. Forty-nine articles reported on incident CHD, coronary artery disease (CAD), and/or MI, of which 15 assessed mortality alone^142,147,153,159,175,185,187,197,202,207,209,213,222,223,225^ and 39 assessed nonfatal cases or a combination of fatal and nonfatal cases.^138,143–145,148,151,153–157,159,160,162,170–172,176,183,189,194–198,200,205,206,208–210,213–215,217,221,224,227,228^ Twenty-six articles examined stroke, of which 7 articles reported on stroke mortality alone^175,185,202,207,222,223,225^ and 19 articles reported on nonfatal stroke or a combination of fatal and nonfatal stroke outcomes.^135,139,146,149,155,159,162,174,179,190,200,203,206,211,212,217,220,221,224^ Less commonly assessed outcomes in this body of evidence included heart failure (9 articles),^137,140,141,180–182,219,222,224^ sudden cardiac death (3 articles),^152,202,221^ peripheral artery disease (PAD; 1 article),^178^ and venous thromboembolism (1 article).^169^

### Evidence synthesis: Adults (Cardiovascular disease endpoint outcomes)

Evidence was synthesized by type of fat, outcome, and study design. Evidence from the PCSs are described in Table 8 whereas evidence from the NCC studies are described in Table 9. The risk of bias assessments for both study designs are described in Table 10.

#### SFA

Thirty-nine articles (38 from PCSs and 1 from a NCC study) assessed the relationship between SFA intake during adulthood and risk of CVD endpoint outcomes.^136,139,140,147,152,156,161,163,167,168,170,178,179,183,186–188,190,191,195–199,201,204,205,212,213,215–218,220–222,226–228^ Of these, 18 articles modeled replacement of SFA with other types of fat or macronutrients,^152,156,163,170,196–198,201,204,205,212,213,215,218,222,226–228^ and six articles examined MUFA:SFA or PUFA:SFA intake ratios.^136,140,161,188,199,216^ Most of the articles reported on either CVD, inclusive of multiple conditions,^136,140,156,161,163,167,168,186,188,191,199,201,204,216,217,221,222,226^ or CHD, CAD, and MI.^147,156,170,183,187,195–198,205,213,215,217,218,221,222,227,228^ Fewer articles reported on stroke,^139,179,190,212,217,220–222^ heart failure,^140,222^ PAD,^178^ or sudden cardiac death.^152,221,222^

##### SFA and total CVD

Among articles that assessed the relationship between SFA intake and CVD without considering replacement, results were predominantly null,^140,163,167,168,186,188,191,216–218^ but some detected associations between higher SFA intake and lower CVD risk,^188,216,221,222^ all of which were conducted in Asia and had participants with, on average, BMI in the normal range. One article reported a statistically significant association between higher SFA intake and greater risk of CVD, but only in women.^218^

When replacement with other types of fat or macronutrients was considered, the pattern of results tended to differ by what macronutrient replaced SFA. When SFA was replaced by total PUFA, results primarily demonstrated associations with lower risk of CVD^163,201,226^ or null associations,^204,226^ with most studies focusing on CVD mortality. One study reported that replacement of SFA with arachidonic acid (AA) was associated with higher risk of CVD mortality, but also found that replacing SFA with LA and marine omega-3 fatty acids was significantly associated with lower risk.^226^ When SFA was replaced with MUFA, results were predominantly null^201,204,226^ or indicated an association with lower risk of CVD.^226^ When SFA was replaced by carbohydrate, one article indicated null associations with CVD,^204^ whereas when carbohydrate was replaced by SFA, two articles indicated associations with greater CVD risk (one only in men).^163,218^ In addition to the studies that examined total SFA intake, two examined the relationship between SFA from food sources and risk of CVD and results were inconsistent.^156,163^ One study (conducted in Spain) reported null associations for SFA from dairy, meat, and eggs, and statistically significant associations with lower risk of CVD with SFA from vegetables and fish/seafood.^163^ The other study (conducted in the U.S.) reported null associations for SFA from butter and plants, and statistically significant associations with lower risk of CVD with SFA from dairy and higher risk of CVD with SFA from meat.^156^ Articles that examined the relationship between the MUFA:SFA or PUFA:SFA intake ratio and CVD reported predominantly null associations,^136,140,161,188,199,216^ although one study reported a higher risk of CVD mortality with a higher PUFA:SFA ratio in men^216^ and another study reported a lower risk of CVD mortality with a higher MUFA:SFA ratio in men or higher total unsaturated fatty acid (UFA):SFA ratio in men and women.^199^

##### SFA and CHD, CAD, MI, or PAD

Several articles assessed the relationship between SFA intake, without considering replacement, and CHD, CAD, and/or MI, and these associations were primarily null^183,187,197,198,217,221,222,228^ or indicated greater risk with higher SFA intake.^147,187,221,228^ Only two of these non-replacement studies reported a statistically significant associations between higher SFA intake and lower risk of CHD, CAD, and/or MI.^198,217^ Regarding types of SFAs, two studies found inconsistent associations between intake of either shorter-chain SFAs of 4 to 10 carbons or longer-chain SFAs of 12 to 18 carbons and risk of CHD/MI.^198,228^ When replacement with other types of fat or macronutrients was considered, the pattern of results tended to differ by the replacing macronutrient. When SFA was replaced by total PUFA, the associated risk of CHD was primarily null^197,198,222^ or lower.^213,228^ Only one study reported a significant association between replacement of SFA with PUFA and higher risk of CHD; however, this article reported small ranges in both SFA and PUFA intake in their cohort.^196^ When SFA was replaced by MUFA, most articles reported null associations with risk of CHD, CAD, or MI,^197,198,222,227,228^ with only two articles reporting associations with higher risk.^196,213^ When SFA was replaced by carbohydrates, including those that specified low, medium or high glycemic index carbohydrates, most articles reported null associations with the risk of CHD, CAD, or MI,^170,197,198,205,222^ but others reported associations with higher risk (particularly with medium or high glycemic index carbohydrates)^170,196^ or lower risk (with whole-grain carbohydrate).^228^ In one study, when carbohydrate was replaced by SFA there was no significant association with fatal or non-fatal CHD.^213^ In the only NCC study to examine the relationship between SFA intake and CVD endpoint outcomes, null associations were detected for incident MI.^195^ In addition to the studies that examined total SFA intake, 5 examined the relationship between SFA from specific food sources, most focusing on meat and dairy, and risk of CHD and MI ^156,196–198,215^. Results tended to vary by the food source of the SFA. Specifically, associations between SFA from meat and CHD, CAD, and MI were null^156,196–198^ or indicated greater risk with higher intake levels^156,198,215^; associations between SFA from dairy, including total dairy, butter, cheese, and milk and CHD, CAD, and MI were null^156,196,197,215^ or indicated lower risk with higher intake levels.^156,196,215^ However, due to the insufficient number of studies that reported on the relationship between SFA from different food sources and CHD, CAD, or MI, results regarding this particular topic remain inconclusive. Only one article addressed PAD, and it detected a null association between SFA intake and incident PAD.^178^

##### SFA and stroke

As indicated previously, few articles assessed the relationship between SFA intake and stroke and most did not model replacement. Among these articles, most exclusively reported null associations between SFA intake and incident total stroke or subtypes of stroke such as ischemic stroke or hemorrhagic stroke.^139,179,190,212,217,220–222^ In three studies, all conducted in Japan among individuals with an average BMI less than 25, higher intake of SFA was associated with lower risk of stroke (one finding significant associations only in men).^190,221,222^ The two studies that modeled replacement of SFA with other types of fat or macronutrients had inconsistent results. One found that replacement of SFA with PUFA, but not MUFA or carbohydrate, was associated with higher risk of stroke mortality,^222^ whereas the other study reported replacement of SFA with LA not being significantly associated with total ischemic stroke and stroke subtypes.^212^

##### SFA and other CVD outcomes

For the remaining outcomes, little evidence was available to draw conclusions. Articles that assessed the relationship between SFA intake and heart failure all reported null associations.^140,222^ Results for sudden cardiac death were inconsistent, with one article reporting greater risk in women with higher SFA intake (but only when replacement with carbohydrates was not modeled),^152^ one article reporting lower risk with higher SFA intake,^221^ and one article reporting null associations.^222^

##### Food sources of SFA and CVD

In addition to the 39 articles that directly assessed SFA intake (reviewed above), five articles (all from European cohorts) indirectly assessed SFA by measuring intake of butter, which is predominantly composed of SFA.^162,176,193,194,206^ The majority of these articles reported null associations between butter intake and CVD,^193,206^ CHD and MI,^162,176,194,206^ or stroke,^162,206^ with only one article reporting an association between higher butter intake and higher risk of CHD in women, but not in men.^162^ However, due to the indirectness of assessing butter intake (compared to directly assessing SFA intake) and the unusual categorizations of butter intake used in one analysis,^194^ these articles were weighed less heavily when drawing conclusions.

#### MUFA

Twenty-nine articles (28 from PCSs and 1 from a NCC study) assessed the relationship between MUFA intake during adulthood and risk of CVD endpoint outcomes.^139,152,161,163,168,179,183,186,188,190,195–199,201,204,205,212,213,215–218,220,222,226–228^ Of these, 16 articles modeled replacement of MUFA with other types of fat or macronutrients^152,163,196–198,201,204,205,212,213,215,218,222,226–228^ and 3 articles examined MUFA:SFA intake ratios.^161,188,199^ Most of the articles reported on either CVD, inclusive of multiple conditions,^161,163,168,186,188,199,201,204,216–218,222,226^ or CHD, CAD, and MI.^183,195–198,205,213,215,217,222,227,228^ Fewer studies assessed stroke^139,179,190,212,217,220,222^ or sudden cardiac death.^152^

##### MUFA and total CVD

Among the articles that assessed the relationship between MUFA intake, without considering replacement, and CVD, results were predominantly null.^168,186,216–218^. However, two articles reported statistically significant associations between higher MUFA intake (one only in women) and lower risk of CVD.^163,218^ Several articles modeled replacement of different types of fat or macronutrients with MUFA and its association with CVD. When SFA was replaced by MUFA, results were null^201,204^ or indicated an association with lower risk of CVD.^163,226^ All three articles that assessed replacement of carbohydrates with MUFA detected an association with lower risk of CVD,^163,218,226^ whereas the one article that assessed replacement of PUFA with MUFA detected an association with higher risk of CVD mortality.^201^ One article considered the food source of MUFA.^226^ When replacement of carbohydrates or SFA with MUFA from plants was modeled, this was associated with lower risk of CVD mortality, whereas when replacement of carbohydrates or SFA with MUFA from animals was modeled, associations indicated higher risk or were null, respectively.^226^

##### MUFA and CHD or MI

Among the articles that assessed the relationship between MUFA intake and CHD or MI without considering replacement, associations were primarily null,^183,195,213,217,227^ including the one NCC study on this topic.^195^ Results were more inconsistent when replacement with other types of dietary fats or macronutrients was considered. Most articles reported null associations between replacement of SFA or carbohydrates with total MUFA, or different sources of MUFA, and CHD or MI.^197,198,205,222,227,228^ However, one article detected higher risk of CHD when carbohydrates or SFA were replaced with total MUFA,^213^ whereas one article detected lower risk of CHD when carbohydrates were replaced with total MUFA.^205^ Two articles considered the food sources of MUFA in their replacement analyses. In one study, replacement of carbohydrate or SFA with MUFA from meat sources was associated with higher risk of CHD, whereas replacement of carbohydrate or SFA with MUFA from dairy sources was associated with lower risk of CHD.^215^ However, in this same article, replacement of MUFA from dairy with MUFA from meat was not associated with CHD.^215^ The other article that considered food sources of MUFA found that replacement of MUFA from animal sources with MUFA from plant sources was associated with lower risk of CHD.^227^

##### MUFA and other CVD outcomes

As indicated previously, few articles assessed the relationship between MUFA intake and stroke, and most did not model replacement. Among the articles that did not model replacement, most detected null associations between MUFA (or, in one case, total unsaturated fatty acid intake^139^) and incident stroke.^139,179,190,217,220^ Only one of five studies detected a significant association between MUFA intake and lower risk of intracerebral hemorrhage; however, this association was only observed in men and MUFA intake only represented intake at breakfast.^190^ The two studies that modeled replacement primarily found that replacement of SFA with MUFA was not associated with stroke mortality,^212,222^ but one study did detect a significantly lower risk of mortality due to small vessel occlusion (but not for other subtypes of stroke).^212^ MUFA intake in women was not associated with sudden cardiac death in the one article that assessed this outcome.^152^

##### Food sources of MUFA and CVD

In addition to the 29 articles that directly assessed MUFA intake (reviewed above), seven articles indirectly assessed MUFA intake by measuring olive oil intake.^143,150,151,164,177,203,207^ Consistent with articles that reported on MUFA from plant sources, results showed either statistically significant associations between greater olive oil intake or use and lower risk of CVD,^150,164,177^ CHD,^143^ or stroke,^203^ or associations were null.^151,207^ However, due to the indirectness of all articles examining MUFA intake by assessing olive oil intake and the non-quantitative categorizations of oil intake (e.g., olive oil used for cooking versus not used for cooking) used in some analyses,^177,203,207^ these articles were weighed less heavily when drawing conclusions.

#### PUFA

Seventy-one articles (67 from PCSs and 4 from NCC studies) assessed the relationship between PUFA intake during adulthood and CVD endpoint outcomes.^136–142,144–146,148,149,152–155,157–160,163,165–169,171–175,178–183,185–190,192,195–202,204,205,208–213,215–220,222–226,228^ Results were synthesized by type of exposure: total PUFA, n-3 PUFA, n-6 PUFA, and n-3:n-6 PUFA ratio.

##### Total PUFA

Thirty-two articles assessed the relationship between total PUFA intake and CVD endpoint outcomes.^136,139,140,152,163,167,168,178,179,183,186–190,195–199,201,204,205,213,215–218,220,222,226,228^ Of these, 14 modeled replacement of other types of fat or macronutrients with total PUFA^152,163,196–198,201,204,205,213,215,218,222,226,228^ and 4 articles examined PUFA:SFA or PUFA+MUFA:SFA intake ratios.^136,140,199,216^ Most articles reported on CHD, CAD, or MI^183,187,189,195–198,205,213,215,217,218,222,228^ or CVD,^136,140,163,167,168,186,188,199,201,204,216,217,222,226^ but some reported on stroke,^139,179,190,217,220,222^ heart failure,^140^ PAD,^178^ or sudden cardiac death.^152^

Total PUFA and total CVD. Among articles that examined the relationship between total PUFA intake, without consideration of replacement, and CVD, results were predominantly null^167,168,186,188,199,204,216,217^ or showed associations with lower risk of CVD.^163,199,201,218^ One study, which was conducted in Japanese men, reported a significant association between higher intake of PUFA and CVD mortality.^216^ As described previously, replacement of SFA with total PUFA was predominantly associated with lower risk of CVD,^163,201,226^ with one article reporting null results.^204^ Similar associations with lower risk of CVD were observed when replacement of MUFA or carbohydrates with PUFA was modeled.^163,201,218,226^ Among the few articles that examined the PUFA:SFA or total UFA:SFA intake ratio, most detected null associations.^136,140,216^

Total PUFA and CHD, CAD, MI, or PAD. Of the articles that examined the relationship between total PUFA intake, without considering replacement, and CHD, CAD, or MI, all reported null^187,189,195,213,217^ associations (including the 2 NCC studies on this topic^189,195^) or beneficial associations.^183,213^ As described previously, when replacement of SFA with PUFA was modeled, primarily null associations^197,198,222^ or associations with lower risk of CHD/MI^213,228^ were detected. Only one article reported an association with higher risk of CHD when replacement of SFA with PUFA was modeled.^196^ Among articles that examined replacement of carbohydrates with PUFA, results were null ^205,213^ or showed associations with lower risk of fatal CHD.^213^ One article examined sources of PUFA, specifically from meat or dairy, and found that replacement of PUFA from dairy with PUFA from meat was not associated with risk of CHD.^215^ However, when PUFA from meat replaced carbohydrates, the associated risk of CHD was higher.^215^ Only one article assessed the relationship between total PUFA intake, without considering replacement, and PAD, and it did not detect a statistically significant association between them.^178^

Total PUFA and stroke or other CVD outcomes. Fewer articles reported on stroke and other CVD outcomes. Of the articles that assessed the relationship between total PUFA intake and risk of stroke without replacement, all detected null associations.^139,179,190,217,220^ Only one article examined the relationship between replacement of SFA with total PUFA and stroke, detecting a statistically significant association with higher risk of mortality.^222^ One study assessed the relationship between total PUFA intake and risk of sudden cardiac death, detecting associations with lower risk, with and without consideration of replacement of carbohydrates.^152^ No articles reported on the relationship between total PUFA intake and heart failure; however, one study assessed the relationship between the PUFA:SFA intake ratio and heart failure and did not detect a statistically significant association.^140^

##### n-3 PUFA

Forty-seven articles assessed the relationship between n-3 PUFA intake and CVD endpoint outcomes.^137,138,141,142,144–146,148,149,152,153,155,157–160,165,166,169,171–175,179–182,185,186,188,189,192,199,200,202,208–211,216–219,223,225,226^ Although some studies reported on total n-3 PUFA intake,^138,152,165,173,175,192,216,218,225,226^ most focused on more specific categories of n-3 PUFAs, namely ALA^141,148,152,155,157,159,165,172,175,179–181,200,202,209,210,218,219,223,225,226^ and EPA, DHA, and docosapentaenoic acid (DPA; alone or in combination as “long chain” n-3 PUFAs).^137,138,141,142,144–146,152,153,157,158,160,165,166,169,171,172,174,175,179,182,185,186,188,189,199,200,202,208–211,217–219,223,225,226^ Few articles modeled replacement between n-3 PUFAs and other types of fat or macronutrients.^152,218,226^ Most articles reported on CHD, CAD, and/or MI,^138,142,144,145,148,153,155,157,159,160,171,172,175,185,189,200,202,209,210,217,218,223,225^ CVD,^142,157–159,165,173,175,185,186,188,192,199,200,202,208,216,217,223,225,226^ or stroke.^146,149,155,159,174,175,179,185,200,202,211,217,223,225^ Fewer articles reported on heart failure,^141,180–182,219^ sudden cardiac death,^152,166,202^ PAD,^137^ or venous thromboembolism.^169^

Total n-3 PUFA. Among articles that assessed total n-3 PUFA intake, including one that considered replacement of carbohydrates or SFA with n-3 PUFA,^226^ most examined CVD incidence and mortality^165,173,175,192,216,218,225,226^ with fewer articles examining CHD, CAD, and/or MI,^138,175,225^ stroke,^175,225^ or sudden cardiac death.^152^ Results were predominantly null across all outcomes,^138,165,173,175,192,216,218,225,226^ with two articles reporting beneficial associations between higher total n-3 PUFA intake and CVD and CHD mortality^175^ or sudden cardiac death.^152^

ALA. Among the articles that examined the relationship between ALA intake and CVD endpoint outcomes, most focused on CHD, CAD, and/or MI,^148,155,157,159,172,175,200,202,209,210,225^ CVD (inclusive of multiple types of outcomes),^157,159,165,175,200,202,210,218,225,226^ and stroke.^149,155,159,175,179,200,202,225^ Fewer reported on heart failure^141,180,181,219^ and sudden cardiac death.^152,202^ In the case of CHD, CAD, or MI and CVD, the majority of articles did not report statistically significant associations with ALA intake^148,155,157,159,165,172,200,202,209,210,218,219,225,226^; only one article reported a beneficial association.^175^ In the case of stroke, results were predominantly null^149,159,179,200,202^ or indicated a beneficial association between ALA intake and stroke.^155,175,225^

EPA, DHA, and DPA. Among the articles that examined EPA, DHA, and/or DPA, most combined EPA and DHA, or EPA, DHA, and DPA, into a single dietary exposure, commonly referring to them collectively as “marine” or “long chain” n-3 PUFAs.^137,141,142,144–146,152,153,157,158,160,165,166,169,171,174,175,179,182,185,188,189,199,200,202,208–211,217–219,223,225,226^ Fewer articles examined EPA,^138,157,160,171,172,211^ DHA,^138,157,160,171,172,185,211^ and DPA^157,160,171,211^ individually. Across articles that assessed the relationship between long chain n-3 PUFA (EPA, DHA, with or without DPA) and CVD endpoint outcomes, most focused on CHD, CAD, and MI or CVD and showed predominantly beneficial associations^144,145,153,157,158,175,199,202,208–210,223,225,226^ (including the one study that modeled replacement of carbohydrates or SFA^226^) or null associations.^142,153,157,160,165,166,171,185,200,210,217^ Only two articles reported detrimental associations with incident CVD.^217,218^ Similar results were observed for articles that assessed the relationship between long chain n-3 PUFA intake and incident stroke, with most reporting null associations^174,179,200,202,211,217^ or beneficial associations.^146,174,175,179,223,225^ One article reported a statistically significant association between greater long chain n-3 PUFA intake and higher risk of stroke; however, this was only observed for cardioembolism and no other types of stroke.^211^ Few articles were included that examined the relationship between total long chain n-3 PUFA intake and heart failure,^137,141,182,219^ sudden cardiac death,^152,202^ or venous thromboembolism^169^ and results were predominantly null across these outcomes, although some reported beneficial associations.^137,152^ When EPA, DHA, or DPA were examined individually, results were less consistent than when they were assessed collectively as long chain n-3 PUFA. In the case of EPA, associations with CHD, CAD, or MI were predominantly null,^138,157,160,171,172^ with only one article showing a detrimental association at the highest quartile of intake for women.^171^ Only one article each examined the relationship between EPA intake and incident CVD and stroke. A beneficial association was detected for CVD^157^ and mixed results were observed for stroke, with a beneficial association detected for stroke due to large artery atherosclerosis, a detrimental association detected for cardioembolism, and null associations detected for small vessel occlusion and total ischemic stroke.^211^ Similar results were seen for DHA, with exclusively null associations detected for CHD, CAD, or MI,^138,157,160,171,172,185^ beneficial associations detected for CVD^157,185^ and associations that varied in direction and statistical significance by type of stroke.^185,211^ Fewer articles assessed DPA individually and results were inconsistent between outcomes. Predominantly null associations were detected between DPA and CHD and MI,^160,171^ although one article reported a beneficial association between them.^157^ In the one article that assessed CVD, an association between higher DPA intake and lower risk of CVD was detected.^157^ In the one article that reported on stroke, predominantly detrimental associations between DPA intake and types of stroke were detected.^211^

##### n-6 PUFA

Sixteen articles assessed the relationship between n-6 PUFA intake and CVD endpoint outcomes.^152,154,157,165,172,173,179,181,192,210,212,216–218,225,226^ Few of these articles modeled replacement between n-6 PUFA and other types of dietary fat or macronutrients.^152,212,218,226^ The majority of articles reported on total n-6 PUFA intake,^152,157,165,173,179,192,216–218,225,226^ but others reported LA intake^152,154,157,165,172,210,212,218,225,226^ and AA intake^152,157,172,218,225,226^ individually. Most articles reported on CHD, CAD, or MI^154,157,172,210,217,218,225^ or CVD.^157,165,173,192,216,217,225,226^ Fewer articles addressed stroke,^179,212,217,225^ heart failure,^181^ or sudden cardiac death.^152^

Total n-6 PUFA. Most articles that examined total n-6 PUFA intake assessed its relationship to CVD, with inconsistent results, detecting beneficial,^173,218,226^ null,^157,192,216,217,225^ and detrimental associations^165,216^ across the articles. Associations between total n-6 PUFA intake and CHD or stroke were null.^157,179,217,225^ Only two articles examined replacement of carbohydrates or SFA with n-6 PUFA, one detecting associations with lower risk of CVD mortality^226^ and the other detecting an association with lower risk of sudden cardiac death.^152^

LA. Associations between LA intake and CVD were predominantly null^157,225^ or indicated lower risk of CVD,^218,226^ with only one article reporting an association with higher risk of CVD.^165^ Associations between LA intake and CHD or stroke were predominantly null,^154,157,172,210,212,225^ with the exception of one article, which reported an association with lower risk of stroke due to small vessel occlusion when MUFA was replaced with LA.^212^ All other associations between replacement of carbohydrates, SFA, or MUFA with LA and total or subtypes of stroke were null.^212^ Only one article reported sudden cardiac death, detecting an association between higher LA intake and lower risk of sudden cardiac death.^152^

AA. Relatively few articles assessed the relationship between AA and CVD endpoint outcomes, with most reporting on CHD or CVD. The majority of articles detected null associations between AA intake on CHD^157,172^ or CVD,^157,218^ however one article reported statistically significant associations with lower risk of CHD and CVD,^225^ whereas another article reported statistically significant associations with higher risk of CVD mortality when carbohydrates or SFA was replaced with AA.^226^ One article each reported on sudden cardiac death^152^ and stroke mortality,^225^ both detecting null associations with AA intake.

##### n-3 to n-6 PUFA Ratio

Three articles, all from PCSs, assessed the relationship between the n-3:n-6 PUFA intake ratio and CVD endpoint outcomes.^165,225,226^ All articles examined incident CVD or CVD mortality,^165,225,226^ with one additionally examining CHD mortality and stroke mortality.^225^ All associations between the n-3:n-6 PUFA intake ratio and CVD endpoint outcomes were null.

#### Dietary Cholesterol

Eleven articles (10 articles from 8 PCSs and 1 article from a NCC study) assessed the relationship between dietary cholesterol intake and CVD endpoint outcomes.^135,140,168,179,184,187,188,195,214,220,224^ Of these, five examined CVD, inclusive of multiple types of outcomes,^140,168,184,188,224^ four examined CHD or MI,^187,195,214,224^ four examined stroke,^135,179,220,224^ and two examined heart failure.^140,224^ For CVD, results were inconsistent. One article, which included multiple large and well-characterized cohorts and used validated diet assessment methods, reported statistically significant associations between higher intake of dietary cholesterol and increased risk of CVD and CVD mortality,^224^ whereas other articles reported statistically significant associations with decreased risk of CVD,^140,184^ or reported null associations.^168,184,188^ Results were also inconsistent for stroke, with some single-sex studies reporting null associations between dietary cholesterol intake and incident stroke in women^220^ and men,^135^ and others reporting statistically significant associations with higher risk of incident stroke.^179,224^ Of the two articles that assessed heart failure, one did not detect significant associations with dietary cholesterol intake,^224^ whereas the other detected a statistically significant association between higher dietary cholesterol intake and lower risk of heart failure in women.^140^ All articles that assessed the relationship between dietary cholesterol intake and CHD or MI reported null associations.^187,195,214,224^ Due to the co-occurrence of dietary cholesterol in foods that are also high in SFA and the relatively low dietary cholesterol intake in several articles,^140,168,220^ it was difficult to disentangle the independent associations between dietary cholesterol and CVD endpoint outcomes in this body of evidence.

#### Assessment of the evidence^x^

As outlined and described below, the body of evidence examining intake of types of dietary fat by adults and CVD endpoint outcomes was assessed for the following elements used when grading the strength of evidence.

##### Risk of Bias

As noted previously, the risk of bias assessment for PCSs and NCC studies in adults are described in Table 10. Nearly all articles were at serious risk of bias due to confounding, with few accounting for all key confounders. In particular, race or ethnicity and family history of CVD or diabetes were not commonly accounted for in this body of evidence. However, many articles accounted for the majority of key confounders, including age, sex, physical activity, smoking, alcohol intake, and total energy intake. All articles were at moderate risk of bias due to selection of reported results as none reported a pre-registered protocol with sufficient information on statistical analysis intentions. Across other domains, the majority of articles were assessed as having low risk of bias.

##### Consistency

The level of consistency across the included articles depended on the type of fat examined, the replacing macronutrient or type of fat (when replacement was modeled), and the CVD outcome assessed. In the case of replacement of SFA with PUFA, findings indicated associations with lower risk of CHD or total CVD or null associations. In the case of replacement of SFA with MUFA or carbohydrates, associations were predominantly null. Because these articles typically only modeled replacement with total MUFA or total carbohydrates, versus differentiating between animal and plant sources of MUFA or simple and complex carbohydrates, this may contribute to the predominantly null results for those analyses. For example, in the few articles that examined specific sources of MUFAs, beneficial associations tended to be observed with plant sources of MUFA, but not with animal sources of MUFA. In the case of PUFA, results tended to vary in consistency by the type of n-3 or n-6 PUFA examined. Although articles that examined total n-3 PUFA showed predominantly null associations with CVD endpoint outcomes, associations between total long chain n-3 PUFA (primarily EPA and DHA) and CVD endpoint outcomes showed more consistent benefits with higher intake. Similarly, although articles that examined total n-6 PUFA intake or LA intake alone tended to show beneficial or null associations with CVD endpoint outcomes, articles that examined AA intake alone were less consistent.

##### Directness

Most studies in this body of evidence were specifically designed to evaluate the relationship between diet and chronic diseases, inclusive of CVD, or CVD specifically. However, several studies were less direct due to a variety of factors. First, although butter and olive oil derive the majority of its calories from dietary fats and are predominantly composed of SFA and MUFA, respectively, articles that examined these foods as exposures were necessarily less direct.^143,150,151,162,164,177,193,194,203,206,207^ Second, several articles were secondary analyses of RCTs originally designed to evaluate exposures or interventions besides types of dietary fats.^142,147,163,164,200,202,205,219^ Third, several cohorts were initially designed to assess outcomes other than CVD, particularly cancer.^148,149,160,162,165,167,170,171,178,191,195,198,203,205,206,208,211,212,217,221^

##### Precision

Power analyses were not reported across this body of evidence. However, although some studies had relatively small sample sizes, the majority of studies had sample sizes greater than 10,000 participants (up to approximately 525,000 participants).

##### Generalizability

The majority of articles reported on studies conducted in the U.S. or in Europe, particularly Scandinavian countries such as Denmark, the Netherlands, and Sweden. Many articles, particularly studies conducted in Europe, did not report race or ethnicity of the cohort. Most articles that did report race or ethnicity had participants who were predominantly White or Caucasian. However, several cohorts from the U.S. had more diverse participants.^156,157,161,168,173,201,224,225^ Few cohorts exclusively recruited participants at high risk of developing CVD,^163,164,184,202^ with most studies enrolling participants across the spectrum of risk. Because several articles excluded individuals with prevalent diabetes, those results may be less generalizable to the overall U.S. population. Several studies conducted in Asia had participants with average BMI in the normal range and lower than the average BMI commonly observed in U.S. cohorts^166,175,185–190,209,216,221,222^; articles from these studies may not be as generalizable to the overall U.S. population in this regard. The majority of articles examined dietary fat intake in adults of middle age or older, therefore, it is possible that results are less generalizable to younger adults.

#### Other important considerations

##### Publication bias

A large, comprehensive search was conducted in multiple databases for this systematic review. Although risk of publication bias is always of potential concern, both relatively small and large studies were included in this review, reporting both null and statistically significant results. Therefore, the risk of publication bias is likely low across this body of evidence.

##### Building on the 2015 Dietary Guidelines Advisory Committee report and conclusions

This systematic review builds and expands on the work of the 2015 Committee, which answered the question, “What is the relationship between intake of saturated fat and risk of cardiovascular disease?” and considered evidence from systematic reviews and meta-analyses, which included RCTs and PCSs from the 1960s to 2010.^xi^ The 2015 Committee drew two conclusions pertaining to CVD endpoint outcomes:

- “Strong and consistent evidence from RCTs and statistical modeling in prospective cohort studies shows that replacing SFA with PUFA reduces the risk of CVD events and coronary mortality. For every 1 percent of energy intake from SFA replaced with PUFA, incidence of CHD is reduced by 2 to 3 percent. However, reducing total fat (replacing total fat with overall carbohydrates) does not lower CVD risk. Consistent evidence from prospective cohort studies shows that higher SFA intake as compared to total carbohydrates is not associated with CVD risk. (Grade: Strong)”
- “Evidence is limited regarding whether replacing SFA with MUFA confers overall CVD (or CVD endpoint) benefits. One reason is that the main sources of MUFA in a typical American diet are animal fat, and because of the co-occurrence of SFA and MUFA in foods makes it difficult to tease out the independent association of MUFA with CVD. However, evidence from RCTs and prospective studies has demonstrated benefits of plant sources of monounsaturated fats, such as olive oil and nuts on CVD risk. (Grade: Limited)”

The evidence in the present review is broadly consistent with these conclusions drawn by the 2015 Committee. In articles that assessed replacement of SFA with PUFA, associations predominantly indicated lower risk of CHD and CVD mortality or were null. However, fewer articles examined outcomes such as heart failure or stroke. In articles that assessed replacement of SFA with carbohydrates, results were inconsistent but predominantly showed null associations with CVD outcomes. Although some articles separated low-, moderate-, and high-glycemic index carbohydrates, most articles did not specify or differentiate between the type of carbohydrate replacing the SFA, including complex carbohydrates or simple carbohydrates. Therefore, little evidence is available to draw conclusions regarding whether the association between replacement of SFA with carbohydrate varies by type of carbohydrate. Based on the evidence in the present review, the 2020 Committee concurred with and updated the conclusions drawn by the 2015 Committee, electing to develop new conclusion statements pertaining to replacement of SFA with PUFA or with carbohydrates to increase specificity of the conclusions. In articles that assessed replacement of SFA with MUFA in the present review, results were predominantly null and did not often differentiate between MUFA from plant sources and MUFA from animal sources. As such, the 2020 Committee concurred with and updated the conclusion drawn by the 2015 Committee regarding replacement of SFA with MUFA.

### Research recommendations

In order to better assess the relationship between intake of dietary fats and risk of CVD, additional research is warranted to:

- Assess whether establishing patterns of dietary fat intake during childhood is predictive of blood lipids and risk of CVD during adulthood
- Examine how pubertal status and sex hormones may modify the effect of dietary fat intake during childhood on blood lipids and risk of CVD during adulthood
- Assess the relationship between replacement of SFA with other types of dietary fats or macronutrients during childhood and risk of CVD
- Examine whether the effect of replacing SFA with carbohydrates on risk of CVD varies by the type of carbohydrate (e.g., simple vs complex carbohydrates)
- Assess the effect of n-6 PUFA, both LA and AA, on risk of CVD
- Assess the effect of n-3 PUFA from plant sources (ALA) on risk of CVD
- Assess whether the relationship between type of dietary fat and blood lipids or risk of CVD varies by the food source or food matrix of the dietary fat
- Employ highly controlled methods (e.g., feeding trials) to examine the effect of dietary cholesterol, independent of SFA, on blood lipids and risk of CVD
- Assess the effect of percentage of types of dietary fats relative to calories within a dietary pattern on blood lipids and risk of CVD during childhood and adulthood
- Assess the effect of participant characteristics, including BMI, race and ethnicity, and chronic disease status, during childhood and adulthood on the relationship between types of dietary fat and blood lipids and risk of CVD
- Provide sufficient control of sodium intake to examine the independent relationship between dietary fat intake and blood pressure during childhood
- Examine the relationship between intake of types of dietary fat intake and specific CVD outcomes, such as heart failure and stroke, in adults instead of assessing CVD in aggregate

### Included articles

1 Altwaijri YA, Day RS, Harrist RB, Dwyer JT, Ausman LM, Labarthe DR. Sexual maturation affects diet-blood total cholesterol association in children: Project HeartBeat! Am J Prev Med. 2009;37(1 Suppl):S65–70. doi:10.1016/j.amepre.2009.04.007.19524158
2 Ballesteros MN, Cabrera RM, Saucedo Mdel S, Fernandez ML. Dietary cholesterol does not increase biomarkers for chronic disease in a pediatric population from northern Mexico. Am J Clin Nutr. 2004;80(4):855–861. doi:10.1093/ajcn/80.4.855.15447890
3 Boreham C, Twisk J, van Mechelen W, Savage M, Strain J, Cran G. Relationships between the development of biological risk factors for coronary heart disease and lifestyle parameters during adolescence: the Northern Ireland Young Hearts Project. Public Health. 1999;113(1):7–12. doi:10.1038/sj.ph.1900526.10823742
4 Cowin IS, Emmett PM. Associations between dietary intakes and blood cholesterol concentrations at 31 months. Eur J Clin Nutr. 2001;55(1):39–49. doi:10.1038/sj.ejcn.1601120.11303493
5 Denke MA, Adams-Huet B, Nguyen AT. Individual cholesterol variation in response to a margarine- or butter-based diet: a study in families. JAMA. 2000;284(21):2740–2747. doi:10.1001/jama.284.21.2740.11105179
6 Dorgan JF, Liu L, Barton BA, . Adolescent diet and metabolic syndrome in young women: results of the Dietary Intervention Study in Children (DISC) follow-up study. J Clin Endocrinol Metab. 2011;96(12):E1999–2008. doi:10.1210/jc.2010-2726.21994964
7 Estevez-Gonzalez MD, Saavedra-Santana P, Betancor-Leon P. Reduction of serum cholesterol and low-density lipoprotein cholesterol levels in a juvenile population after isocaloric substitution of whole milk with a milk preparation (skimmed milk enriched with oleic acid). J Pediatr. 1998;132(1):85–89. doi:10.1016/s0022-3476(98)70490-1.9470006
8 Hakanen M, Lagstrom H, Pahkala K, . Dietary and lifestyle counselling reduces the clustering of overweight-related cardiometabolic risk factors in adolescents. Acta Paediatr. 2010;99(6):888–895. doi:10.1111/j.1651-2227.2009.01636.x.20002624
9 Harris C, Buyken A, Koletzko S, . Dietary fatty acids and changes in blood lipids during adolescence: the role of substituting nutrient intakes. Nutrients. 2017;9(2). doi:10.3390/nu9020127.
10 Kaitosaari T, Ronnemaa T, Raitakari O, . Effect of 7-year infancy-onset dietary intervention on serum lipoproteins and lipoprotein subclasses in healthy children in the prospective, randomized Special Turku Coronary Risk Factor Intervention Project for Children (STRIP) study. Circulation. 2003;108(6):672–677. doi:10.1161/01.Cir.0000083723.75065.D4.12885748
11 Kaitosaari T, Ronnemaa T, Viikari J, . Low-saturated fat dietary counseling starting in infancy improves insulin sensitivity in 9-year-old healthy children: the Special Turku Coronary Risk Factor Intervention Project for Children (STRIP) study. Diabetes Care. 2006;29(4):781–785. doi:10.2337/diacare.29.04.06.dc05-1523.16567815
12 Khalil H, Murrin C, O’Reilly M, . Total HDL cholesterol efflux capacity in healthy children - associations with adiposity and dietary intakes of mother and child. Nutr Metab Cardiovasc Dis. 2017;27(1):70–77. doi:10.1016/j.numecd.2016.10.002.27919542
13 Kwiterovich PO, Hartmuller G, Van Horn L, . Efficacy and safety of lowering dietary intake of fat and cholesterol in children with elevated low-density lipoprotein cholesterol: The Dietary Intervention Study in Children (DISC). JAMA. 1995;273(18):1429–1435. doi:10.1001/jama.1995.03520420045036.7723156
14 Lapinleimu H, Viikari J, Jokinen E, . Prospective randomised trial in 1062 infants of diet low in saturated fat and cholesterol. Lancet. 1995;345(8948):471–476. doi:10.1016/s0140-6736(95)90580-4.7861873
15 Lehtovirta M, Pahkala K, Niinikoski H, . Effect of dietary counseling on a comprehensive metabolic profile from childhood to adulthood. J Pediatr. 2018;195:190–198.e193. doi:10.1016/j.jpeds.2017.11.057.29397160
16 Magnussen CG, Thomson R, Cleland VJ, Ukoumunne OC, Dwyer T, Venn A. Factors affecting the stability of blood lipid and lipoprotein levels from youth to adulthood: evidence from the Childhood Determinants of Adult Health Study. Arch Pediatr Adolesc Med. 2011;165(1):68–76. doi:10.1001/archpediatrics.2010.246.21199983
17 Masquio DC, de Piano A, Campos RM, . Reduction in saturated fat intake improves cardiovascular risks in obese adolescents during interdisciplinary therapy. Int J Clin Pract. 2015;69(5):560–570. doi:10.1111/ijcp.12573.25296762
18 Muros JJ, Zabala M, Oliveras-Lopez MJ, . Effect of physical activity, nutritional education, and consumption of extra virgin olive oil on lipid, physiological, and anthropometric profiles in a pediatric population. J Phys Act Health. 2015;12(9):1245–1252. doi:10.1123/jpah.2014-0236.25409189
19 Ness AR, Maynard M, Frankel S, . Diet in childhood and adult cardiovascular and all cause mortality: the Boyd Orr cohort. Heart. 2005;91(7):894–898. doi:10.1136/hrt.2004.043489.15958357
20 Nicklas TA, Dwyer J, Feldman HA, Luepker RV, Kelder SH, Nader PR. Serum cholesterol levels in children are associated with dietary fat and fatty acid intake. J Am Diet Assoc. 2002;102(4):511–517. doi:10.1016/s0002-8223(02)90117-3.11985407
21 Niinikoski H, Jula A, Viikari J, . Blood pressure is lower in children and adolescents with a low-saturated-fat diet since infancy: the special turku coronary risk factor intervention project. Hypertension. 2009;53(6):918–924. doi:10.1161/hypertensionaha.109.130146.19364991
22 Niinikoski H, Lagstrom H, Jokinen E, . Impact of repeated dietary counseling between infancy and 14 years of age on dietary intakes and serum lipids and lipoproteins: the STRIP study. Circulation. 2007;116(9):1032–1040. doi:10.1161/circulationaha.107.699447.17698729
23 Niinikoski H, Pahkala K, Ala-Korpela M, . Effect of repeated dietary counseling on serum lipoproteins from infancy to adulthood. Pediatrics. 2012;129(3):e704–713. doi:10.1542/peds.2011-1503.22331346
24 Nupponen M, Pahkala K, Juonala M, . Metabolic syndrome from adolescence to early adulthood: effect of infancy-onset dietary counseling of low saturated fat: the Special Turku Coronary Risk Factor Intervention Project (STRIP). Circulation. 2015;131(7):605–613. doi:10.1161/circulationaha.114.010532.25605660
25 Obarzanek E, Kimm SY, Barton BA, . Long-term safety and efficacy of a cholesterol-lowering diet in children with elevated low-density lipoprotein cholesterol: seven-year results of the Dietary Intervention Study in Children (DISC). Pediatrics. 2001;107(2):256–264. doi:10.1542/peds.107.2.256.11158455
26 Post GB, Kemper HC, Twisk J, van Mechelen W. The association between dietary patterns and cardio vascular disease risk indicators in healthy youngsters: results covering fifteen years of longitudinal development. Eur J Clin Nutr. 1997;51(6):387–393. doi:10.1038/sj.ejcn.1600419.9192197
27 Quivers ES, Driscoll DJ, Garvey CD, . Variability in response to a low-fat, low-cholesterol diet in children with elevated low-density lipoprotein cholesterol levels. Pediatrics. 1992;89(5 Pt 1):925–929. Published 1992/05/01.1579405
28 Raitakari OT, Ronnemaa T, Jarvisalo MJ, . Endothelial function in healthy 11-year-old children after dietary intervention with onset in infancy: the Special Turku Coronary Risk Factor Intervention Project for children (STRIP). Circulation. 2005;112(24):3786–3794. doi:10.1161/circulationaha.105.583195.16330680
29 Rask-Nissila L, Jokinen E, Ronnemaa T, . Prospective, randomized, infancy-onset trial of the effects of a low-saturated-fat, low-cholesterol diet on serum lipids and lipoproteins before school age: The Special Turku Coronary Risk Factor Intervention Project (STRIP). Circulation. 2000;102(13):1477–1483. doi:10.1161/01.cir.102.13.1477.11004136
30 Routi T, Ronnemaa T, Salo P, . Effects of prospective, randomized cholesterol-lowering dietary intervention and apolipoprotein E phenotype on serum lipoprotein(a) concentrations of infants aged 7-24 mo. Am J Clin Nutr. 1996;63(3):386–391. doi:10.1093/ajcn/63.3.386.8602597
31 Simell O, Niinikoski H, Ronnemaa T, . Special Turku Coronary Risk Factor Intervention Project for Babies (STRIP). Am J Clin Nutr. 2000;72(5 Suppl):1316s–1331s. doi:10.1093/ajcn/72.5.1316s.11063474
32 Simons-Morton DG, Hunsberger SA, Van Horn L, . Nutrient intake and blood pressure in the Dietary Intervention Study in Children. Hypertension. 1997;29(4):930–936. doi:10.1161/01.hyp.29.4.930.9095079
33 Stroobant W, Braun KV, Kiefte-de Jong JC, . Intake of different types of fatty acids in infancy is not associated with growth, adiposity, or cardiometabolic health up to 6 years of Age. J Nutr. 2017;147(3):413–420. doi:10.3945/jn.116.241018.28122928
34 Twisk JW, Kemper HC, Mellenbergh GJ, van Mechelen W, Post GB. Relation between the longitudinal development of lipoprotein levels and lifestyle parameters during adolescence and young adulthood. Ann Epidemiol. 1996;6(3):246–256. doi:10.1016/1047-2797(96)00003-8.8827160
35 van den Hooven EH, de Jonge LL, Kiefte-de Jong JC, . Infant macronutrient composition is associated with differences in cardiovascular structures and function in childhood. J Nutr. 2013;143(12):1989–1998. doi:10.3945/jn.113.179440.24068791
36 Vuholm S, Rantanen JM, Teisen MN, . Effects of oily fish intake on cardiometabolic markers in healthy 8- to 9-y-old children: The FiSK Junior randomized trial. Am J Clin Nutr. 2019;110(6):1296–1305. doi:10.1093/ajcn/nqz233.31595295
37 Williams CL, Strobino BA. Childhood diet, overweight, and CVD risk factors: The Healthy Start project. Prev Cardiol. 2008;11(1):11–20. doi:10.1111/j.1520-037x.2007.06677.x.18174786
38 Abbaspour N, Roberts T, Hooshmand S, Kern M, Hong MY. Mixed nut consumption may improve cardiovascular disease risk factors in overweight and obese adults. Nutrients. 2019;11(7). doi:10.3390/nu11071488.
39 Abdullah MM, Cyr A, Lepine MC, . Recommended dairy product intake modulates circulating fatty acid profile in healthy adults: a multi-centre cross-over study. Br J Nutr. 2015;113(3):435–444. doi:10.1017/s0007114514003894.25609231
40 Adams TH, Walzem RL, Smith DR, Tseng S, Smith SB. Hamburger high in total, saturated and trans-fatty acids decreases HDL cholesterol and LDL particle diameter, and increases TAG, in mildly hypercholesterolaemic men. Br J Nutr. 2010;103(1):91–98. doi:10.1017/s0007114509991516.19674491
41 Akrami A, Nikaein F, Babajafari S, Faghih S, Yarmohammadi H. Comparison of the effects of flaxseed oil and sunflower seed oil consumption on serum glucose, lipid profile, blood pressure, and lipid peroxidation in patients with metabolic syndrome. J Clin Lipidol. 2018;12(1):70–77. doi:10.1016/j.jacl.2017.11.004.29229363
42 Alphonse PA, Ramprasath V, Jones PJ. Effect of dietary cholesterol and plant sterol consumption on plasma lipid responsiveness and cholesterol trafficking in healthy individuals. Br J Nutr. 2017;117(1):56–66. doi:10.1017/s0007114516004530.28112077
43 Andraski AB, Singh SA, Lee LH, . Effects of replacing dietary monounsaturated fat with carbohydrate on HDL (high-density lipoprotein) protein metabolism and proteome composition in humans. Arterioscler Thromb Vasc Biol. 2019;39(11):2411–2430. doi:10.1161/atvbaha.119.312889.31554421
44 Annuzzi G, Bozzetto L, Costabile G, . Diets naturally rich in polyphenols improve fasting and postprandial dyslipidemia and reduce oxidative stress: a randomized controlled trial. Am J Clin Nutr. 2014;99(3):463–471. doi:10.3945/ajcn.113.073445.24368433
45 Baer DJ, Novotny JA. Consumption of cashew nuts does not influence blood lipids or other markers of cardiovascular disease in humans: a randomized controlled trial. Am J Clin Nutr. 2019;109(2):269–275. doi:10.1093/ajcn/nqy242.30753323
46 Barbour JA, Howe PR, Buckley JD, Bryan J, Coates AM. Effect of 12 weeks high oleic peanut consumption on cardio-metabolic risk factors and body composition. Nutrients. 2015;7(9):7381–7398. doi:10.3390/nu7095343.26404365
47 Baxheinrich A, Stratmann B, Lee-Barkey YH, Tschoepe D, Wahrburg U. Effects of a rapeseed oil-enriched hypoenergetic diet with a high content of alpha-linolenic acid on body weight and cardiovascular risk profile in patients with the metabolic syndrome. Br J Nutr. 2012;108(4):682–691. doi:10.1017/s0007114512002875.22894911
48 Beavers KM, Serra MC, Beavers DP, Hudson GM, Willoughby DS. The lipid-lowering effects of 4 weeks of daily soymilk or dairy milk ingestion in a postmenopausal female population. J Med Food. 2010;13(3):650–656. doi:10.1089/jmf.2009.0171.20521988
49 Bergeron N, Chiu S, Williams PT, S M K, Krauss RM. Effects of red meat, white meat, and nonmeat protein sources on atherogenic lipoprotein measures in the context of low compared with high saturated fat intake: a randomized controlled trial. Am J Clin Nutr. 2019;110(1):24–33. doi:10.1093/ajcn/nqz035.31161217
50 Bjermo H, Iggman D, Kullberg J, . Effects of n-6 PUFAs compared with SFAs on liver fat, lipoproteins, and inflammation in abdominal obesity: a randomized controlled trial. Am J Clin Nutr. 2012;95(5):1003–1012. doi:10.3945/ajcn.111.030114.22492369
51 Bladbjerg EM, Larsen TM, Due A, Stender S, Astrup A, Jespersen J. Effects on markers of inflammation and endothelial cell function of three ad libitum diets differing in type and amount of fat and carbohydrate: a 6-month randomised study in obese individuals. Br J Nutr. 2011;106(1):123–129. doi:10.1017/s0007114510005829.21320366
52 Blesso CN, Andersen CJ, Barona J, Volek JS, Fernandez ML. Whole egg consumption improves lipoprotein profiles and insulin sensitivity to a greater extent than yolk-free egg substitute in individuals with metabolic syndrome. Metabolism. 2013;62(3):400–410. doi:10.1016/j.metabol.2012.08.014.23021013
53 Bos MB, de Vries JH, Feskens EJ, . Effect of a high monounsaturated fatty acids diet and a Mediterranean diet on serum lipids and insulin sensitivity in adults with mild abdominal obesity. Nutr Metab Cardiovasc Dis. 2010;20(8):591–598. doi:10.1016/j.numecd.2009.05.008.19692213
54 Bowen KJ, Kris-Etherton PM, West SG, . Diets enriched with conventional or high-oleic acid canola oils lower atherogenic lipids and lipoproteins compared to a diet with a Western fatty acid profile in adults with central adiposity. J Nutr. 2019;149(3):471–478. doi:10.1093/jn/nxy307.30773586
55 Brassard D, Tessier-Grenier M, Allaire J, . Comparison of the impact of SFAs from cheese and butter on cardiometabolic risk factors: a randomized controlled trial. Am J Clin Nutr. 2017;105(4):800–809. doi:10.3945/ajcn.116.150300.28251937
56 Burns-Whitmore B, Haddad E, Sabate J, Rajaram S. Effects of supplementing n-3 fatty acid enriched eggs and walnuts on cardiovascular disease risk markers in healthy free-living lacto-ovo-vegetarians: a randomized, crossover, free-living intervention study. Nutr J. 2014;13:29. doi:10.1186/1475-2891-13-29.24673793
57 Cheng C, Wang D, Xia H, . A comparative study of the effects of palm olein, cocoa butter and extra virgin olive oil on lipid profile, including low-density lipoprotein subfractions in young healthy Chinese people. Int J Food Sci Nutr. 2019;70(3):355–366. doi:10.1080/09637486.2018.1504009.30160543
58 Chinwong S, Chinwong D, Mangklabruks A. Daily consumption of virgin coconut oil increases high-density lipoprotein cholesterol levels in healthy volunteers: a randomized crossover trial. Evid Based Complement Alternat Med. 2017;2017:7251562. doi:10.1155/2017/7251562.29387131
59 Chiu S, Williams PT, Dawson T, . Diets high in protein or saturated fat do not affect insulin sensitivity or plasma concentrations of lipids and lipoproteins in overweight and obese adults. J Nutr. 2014;144(11):1753–1759. doi:10.3945/jn.114.197624.25332473
60 Choi SH, Gharahmany G, Walzem RL, Meade TH, Smith SB. Ground beef high in total fat and saturated fatty acids decreases X receptor signaling targets in peripheral blood mononuclear cells of men and women. Lipids. 2018;53(3):279–290. doi:10.1002/lipd.12028.29663407
61 Clayton ZS, Scholar KR, Shelechi M, . Influence of resistance training combined with daily consumption of an egg-based or bagel-based breakfast on risk factors for chronic diseases in healthy untrained individuals. J Am Coll Nutr. 2015;34(2):113–119. doi:10.1080/07315724.2014.946622.25785868
62 Dawczynski C, Martin L, Wagner A, Jahreis G. n-3 LC-PUFA-enriched dairy products are able to reduce cardiovascular risk factors: a double-blind, cross-over study. Clin Nutr. 2010;29(5):592–599. doi:10.1016/j.clnu.2010.02.008.20304540
63 de Souza RGM, Gomes AC, de Castro IA, Mota JF. A baru almond-enriched diet reduces abdominal adiposity and improves high-density lipoprotein concentrations: a randomized, placebo-controlled trial. Nutrition. 2018;55–56:154–160. doi:10.1016/j.nut.2018.06.001.
64 Dhillon J, Thorwald M, De La Cruz N, . Glucoregulatory and cardiometabolic profiles of almond vs. cracker snacking for 8 weeks in young adults: a randomized controlled trial. Nutrients. 2018;10(8). doi:10.3390/nu10080960.
65 Dias CB, Amigo N, Wood LG, Correig X, Garg ML. Effect of diets rich in either saturated fat or n-6 polyunsaturated fatty acids and supplemented with long-chain n-3 polyunsaturated fatty acids on plasma lipoprotein profiles. Eur J Clin Nutr. 2017;71(11):1297–1302. doi:10.1038/ejcn.2017.56.28488685
66 Drouin-Chartier JP, Gagnon J, Labonte ME, . Impact of milk consumption on cardiometabolic risk in postmenopausal women with abdominal obesity. Nutr J. 2015;14:12. doi:10.1186/1475-2891-14-12.25604722
67 Egert S, Kratz M, Kannenberg F, Fobker M, Wahrburg U. Effects of high-fat and low-fat diets rich in monounsaturated fatty acids on serum lipids, LDL size and indices of lipid peroxidation in healthy non-obese men and women when consumed under controlled conditions. Eur J Nutr. 2011;50(1):71–79. doi:10.1007/s00394-010-0116-9.20521076
68 Engel S, Tholstrup T. Butter increased total and LDL cholesterol compared with olive oil but resulted in higher HDL cholesterol compared with a habitual diet. Am J Clin Nutr. 2015;102(2):309–315. doi:10.3945/ajcn.115.112227.26135349
69 Faghihnia N, Tsimikas S, Miller ER, Witztum JL, Krauss RM. Changes in lipoprotein(a), oxidized phospholipids, and LDL subclasses with a low-fat high-carbohydrate diet. J Lipid Res. 2010;51(11):3324–3330. doi:10.1194/jlr.M005769.20713651
70 Farajbakhsh A, Mazloomi SM, Mazidi M, . Sesame oil and vitamin E co-administration may improve cardiometabolic risk factors in patients with metabolic syndrome: a randomized clinical trial. Eur J Clin Nutr. 2019;73(10):1403–1411. doi:10.1038/s41430-019-0438-5.31089253
71 Gagliardi AC, Maranhao RC, de Sousa HP, Schaefer EJ, Santos RD. Effects of margarines and butter consumption on lipid profiles, inflammation markers and lipid transfer to HDL particles in free-living subjects with the metabolic syndrome. Eur J Clin Nutr. 2010;64(10):1141–1149. doi:10.1038/ejcn.2010.122.20648041
72 Gilmore LA, Walzem RL, Crouse SF, . Consumption of high-oleic acid ground beef increases HDL-cholesterol concentration but both high- and low-oleic acid ground beef decrease HDL particle diameter in normocholesterolemic men. J Nutr. 2011;141(6):1188–1194. doi:10.3945/jn.110.136085.21525253
73 Grieger JA, Miller MD, Cobiac L. Investigation of the effects of a high fish diet on inflammatory cytokines, blood pressure, and lipids in healthy older Australians. Food Nutr Res. 2014;58. doi:10.3402/fnr.v58.20369.
74 Hagen IV, Helland A, Bratlie M, . High intake of fatty fish, but not of lean fish, affects serum concentrations of TAG and HDL-cholesterol in healthy, normal-weight adults: a randomised trial. Br J Nutr. 2016;116(4):648–657. doi:10.1017/s0007114516002555.27363518
75 Hallund J, Madsen BO, Bugel SH, . The effect of farmed trout on cardiovascular risk markers in healthy men. Br J Nutr. 2010;104(10):1528–1536. doi:10.1017/s0007114510002527.20594395
76 Harris M, Hutchins A, Fryda L. The impact of virgin coconut oil and high-oleic safflower oil on body composition, lipids, and inflammatory markers in postmenopausal women. J Med Food. 2017;20(4):345–351. doi:10.1089/jmf.2016.0114.28277823
77 Hyde PN, Sapper TN, Crabtree CD, . Dietary carbohydrate restriction improves metabolic syndrome independent of weight loss. JCI Insight. 2019;4(12). doi:10.1172/jci.insight.128308.
78 Iggman D, Rosqvist F, Larsson A, . Role of dietary fats in modulating cardiometabolic risk during moderate weight gain: a randomized double-blind overfeeding trial (LIPOGAIN study). J Am Heart Assoc. 2014;3(5):e001095. doi:10.1161/jaha.114.001095.25319187
79 Intorre F, Foddai MS, Azzini E, . Differential effect of cheese fatty acid composition on blood lipid profile and redox status in normolipidemic volunteers: a pilot study. Int J Food Sci Nutr. 2011;62(6):660–669. doi:10.3109/09637486.2011.569491.21591986
80 Isherwood C, Wong M, Jones WS, Davies IG, Griffin BA. Lack of effect of cold water prawns on plasma cholesterol and lipoproteins in normo-lipidaemic men. Cell Mol Biol (Noisy-le-grand). 2010;56(1):52–58. doi:10.1170/T879.20196970
81 Jaakkola JM, Pahkala K, Ronnemaa T, . Longitudinal child-oriented dietary intervention: association with parental diet and cardio-metabolic risk factors. The Special Turku Coronary Risk Factor Intervention Project. Eur J Prev Cardiol. 2017;24(16):1779–1787. doi:10.1177/2047487317720286.28727955
82 Jebb SA, Lovegrove JA, Griffin BA, . Effect of changing the amount and type of fat and carbohydrate on insulin sensitivity and cardiovascular risk: the RISCK (Reading, Imperial, Surrey, Cambridge, and Kings) trial. Am J Clin Nutr. 2010;92(4):748–758. doi:10.3945/ajcn.2009.29096.20739418
83 Jones PJ, Senanayake VK, Pu S, . DHA-enriched high-oleic acid canola oil improves lipid profile and lowers predicted cardiovascular disease risk in the canola oil multicenter randomized controlled trial. Am J Clin Nutr. 2014;100(1):88–97. doi:10.3945/ajcn.113.081133.24829493
84 Kalgaonkar S, Almario RU, Gurusinghe D, . Differential effects of walnuts vs almonds on improving metabolic and endocrine parameters in PCOS. Eur J Clin Nutr. 2011;65(3):386–393. doi:10.1038/ejcn.2010.266.21157477
85 Karupaiah T, Chuah KA, Chinna K, . Comparing effects of soybean oil- and palm olein-based mayonnaise consumption on the plasma lipid and lipoprotein profiles in human subjects: a double-blind randomized controlled trial with cross-over design. Lipids Health Dis. 2016;15(1):131. doi:10.1186/s12944-016-0301-9.27535127
86 Katz DL, Davidhi A, Ma Y, Kavak Y, Bifulco L, Njike VY. Effects of walnuts on endothelial function in overweight adults with visceral obesity: a randomized, controlled, crossover trial. J Am Coll Nutr. 2012;31(6):415–423. doi:10.1080/07315724.2012.10720468.23756586
87 Kawakami Y, Yamanaka-Okumura H, Naniwa-Kuroki Y, Sakuma M, Taketani Y, Takeda E. Flaxseed oil intake reduces serum small dense low-density lipoprotein concentrations in Japanese men: a randomized, double blind, crossover study. Nutr J. 2015;14:39. doi:10.1186/s12937-015-0023-2.25896182
88 Khaw KT, Sharp SJ, Finikarides L, . Randomised trial of coconut oil, olive oil or butter on blood lipids and other cardiovascular risk factors in healthy men and women. BMJ Open. 2018;8(3):e020167. doi:10.1136/bmjopen-2017-020167.
89 Klempel MC, Kroeger CM, Varady KA. Alternate day fasting increases LDL particle size independently of dietary fat content in obese humans. Eur J Clin Nutr. 2013;67(7):783–785. doi:10.1038/ejcn.2013.83.23612508
90 Kontogianni MD, Vlassopoulos A, Gatzieva A, . Flaxseed oil does not affect inflammatory markers and lipid profile compared to olive oil, in young, healthy, normal weight adults. Metabolism. 2013;62(5):686–693. doi:10.1016/j.metabol.2012.11.007.23347535
91 Kovell LC, Yeung EH, Miller ER, 3rd, . Healthy diet reduces markers of cardiac injury and inflammation regardless of macronutrients: results from the OmniHeart trial. Int J Cardiol. 2020;299:282–288. doi:10.1016/j.ijcard.2019.07.102.31447226
92 Kruse M, von Loeffelholz C, Hoffmann D, . Dietary rapeseed/canola-oil supplementation reduces serum lipids and liver enzymes and alters postprandial inflammatory responses in adipose tissue compared to olive-oil supplementation in obese men. Mol Nutr Food Res. 2015;59(3):507–519. doi:10.1002/mnfr.201400446.25403327
93 Lim SS, Noakes M, Keogh JB, Clifton PM. Long-term effects of a low carbohydrate, low fat or high unsaturated fat diet compared to a no-intervention control. Nutr Metab Cardiovasc Dis. 2010;20(8):599–607. doi:10.1016/j.numecd.2009.05.003.19692216
94 Liu X, Garban J, Jones PJ, . Diets low in saturated fat with different unsaturated fatty acid profiles similarly increase serum-mediated cholesterol efflux from THP-1 macrophages in a population with or at risk for metabolic syndrome: the Canola Oil Multicenter Intervention Trial. J Nutr. 2018;148(5):721–728. doi:10.1093/jn/nxy040.30053283
95 Lucci P, Borrero M, Ruiz A, . Palm oil and cardiovascular disease: a randomized trial of the effects of hybrid palm oil supplementation on human plasma lipid patterns. Food Funct. 2016;7(1):347–354. doi:10.1039/c5fo01083g.26488229
96 Lv C, Wang Y, Zhou C, . Effects of dietary palm olein on the cardiovascular risk factors in healthy young adults. Food Nutr Res. 2018;62. doi:10.29219/fnr.v62.1353.
97 McDaniel J, Askew W, Bennett D, . Bison meat has a lower atherogenic risk than beef in healthy men. Nutr Res. 2013;33(4):293–302. doi:10.1016/j.nutres.2013.01.007.23602247
98 McKay DL, Eliasziw M, Chen CYO, Blumberg JB. A pecan-rich diet improves cardiometabolic risk factors in overweight and obese adults: a randomized controlled trial. Nutrients. 2018;10(3). doi:10.3390/nu10030339.
99 Michielsen C, Hangelbroek RWJ, Feskens EJM, Afman LA. Disentangling the effects of monounsaturated fatty acids from other components of a Mediterranean diet on serum metabolite profiles: a randomized fully controlled dietary intervention in healthy subjects at risk of the metabolic syndrome. Mol Nutr Food Res. 2019;63(9):e1801095. doi:10.1002/mnfr.201801095.30725537
100 Miller M, Sorkin JD, Mastella L, . Poly is more effective than monounsaturated fat for dietary management in the metabolic syndrome: the muffin study. J Clin Lipidol. 2016;10(4):996–1003. doi:10.1016/j.jacl.2016.04.011.27578132
101 Missimer A, DiMarco DM, Andersen CJ, Murillo AG, Vergara-Jimenez M, Fernandez ML. Consuming two eggs per day, as compared to an oatmeal breakfast, decreases plasma ghrelin while maintaining the LDL/HDL ratio. Nutrients. 2017;9(2). doi:10.3390/nu9020089.
102 Morillas-Ruiz JM, Delgado-Alarcon JM, Rubio-Perez JM, Albaladejo Oton MD. The type of fat ingested at breakfast influences the plasma lipid profile of postmenopausal women. Biomed Res Int. 2014;2014:815915. doi:10.1155/2014/815915.25136625
103 Morton AM, Furtado JD, Mendivil CO, Sacks FM. Dietary unsaturated fat increases HDL metabolic pathways involving apoE favorable to reverse cholesterol transport. JCI Insight. 2019;4(7). doi:10.1172/jci.insight.124620.
104 Ng YT, Voon PT, Ng TKW, . Interesterified palm olein (IEPalm) and interesterified stearic acid-rich fat blend (IEStear) have no adverse effects on insulin resistance: a randomized control trial. Nutrients. 2018;10(8). doi:10.3390/nu10081112.
105 Olmedilla-Alonso B, Nova-Rebato E, Garcia-Gonzalez N, . Effect of ewe’s (semi-skimmed and whole) and cow’s milk yogurt consumption on the lipid profile of control subjects: a crossover study. Food Nutr Res. 2017;61(1):1391669. doi:10.1080/16546628.2017.1391669.29151833
106 Ooi EM, Lichtenstein AH, Millar JS, . Effects of therapeutic lifestyle change diets high and low in dietary fish-derived FAs on lipoprotein metabolism in middle-aged and elderly subjects. J Lipid Res. 2012;53(9):1958–1967. doi:10.1194/jlr.P024315.22773687
107 Palacios OM, Maki KC, Xiao D, . Effects of consuming almonds on insulin sensitivity and other cardiometabolic health markers in adults with prediabetes. J Am Coll Nutr. 2019:1–10. doi:10.1080/07315724.2019.1660929.
108 Palomaki A, Pohjantahti-Maaroos H, Wallenius M, . Effects of dietary cold-pressed turnip rapeseed oil and butter on serum lipids, oxidized LDL and arterial elasticity in men with metabolic syndrome. Lipids Health Dis. 2010;9:137. doi:10.1186/1476-511x-9-137.21122147
109 Pieters DJ, Mensink RP. Effects of stearidonic acid on serum triacylglycerol concentrations in overweight and obese subjects: a randomized controlled trial. Eur J Clin Nutr. 2015;69(1):121–126. doi:10.1038/ejcn.2014.193.25226826
110 Raziani F, Tholstrup T, Kristensen MD, . High intake of regular-fat cheese compared with reduced-fat cheese does not affect LDL cholesterol or risk markers of the metabolic syndrome: a randomized controlled trial. Am J Clin Nutr. 2016;104(4):973–981. doi:10.3945/ajcn.116.134932.27557654
111 Root MM, Dawson HR. DASH-like diets high in protein or monounsaturated fats improve metabolic syndrome and calculated vascular risk. Int J Vitam Nutr Res. 2013;83(4):224–231. doi:10.1024/0300-9831/a000164.25008012
112 Rozati M, Barnett J, Wu D, . Cardio-metabolic and immunological impacts of extra virgin olive oil consumption in overweight and obese older adults: a randomized controlled trial. Nutr Metab (Lond). 2015;12:28. doi:10.1186/s12986-015-0022-5.26251666
113 Rueda JM, Khosla P. Impact of breakfasts (with or without eggs) on body weight regulation and blood lipids in university students over a 14-week semester. Nutrients. 2013;5(12):5097–5113. doi:10.3390/nu5125097.24352089
114 Sari I, Baltaci Y, Bagci C, . Effect of pistachio diet on lipid parameters, endothelial function, inflammation, and oxidative status: a prospective study. Nutrition. 2010;26(4):399–404. doi:10.1016/j.nut.2009.05.023.19647416
115 Sawrey-Kubicek L, Zhu C, Bardagjy AS, . Whole egg consumption compared with yolk-free egg increases the cholesterol efflux capacity of high-density lipoproteins in overweight, postmenopausal women. Am J Clin Nutr. 2019;110(3):617–627. doi:10.1093/ajcn/nqz088.31172172
116 Sofi F, Buccioni A, Cesari F, . Effects of a dairy product (pecorino cheese) naturally rich in cis-9, trans-11 conjugated linoleic acid on lipid, inflammatory and haemorheological variables: a dietary intervention study. Nutr Metab Cardiovasc Dis. 2010;20(2):117–124. doi:10.1016/j.numecd.2009.03.004.19473822
117 Sofi F, Giorgi G, Cesari F, . The atherosclerotic risk profile is affected differently by fish flesh with a similar EPA and DHA content but different n-6/n-3 ratio. Asia Pac J Clin Nutr. 2013;22(1):32–40. doi:10.6133/apjcn.2013.22.1.12.23353608
118 Stonehouse W, Benassi-Evans B, James-Martin G, Abeywardena M. Fatty acid regio-specificity of triacylglycerol molecules may affect plasma lipid responses to dietary fats-a randomised controlled cross-over trial. Eur J Clin Nutr. 2020;74(2):268–277. doi:10.1038/s41430-019-0452-7.31227804
119 Sun G, Xia H, Yang Y, . Effects of palm olein and olive oil on serum lipids in a Chinese population: a randomized, double-blind, cross-over trial. Asia Pac J Clin Nutr. 2018;27(3):572–580. doi:10.6133/apjcn.032017.12.29737804
120 Tapsell L, Batterham M, Huang XF, . Short term effects of energy restriction and dietary fat sub-type on weight loss and disease risk factors. Nutr Metab Cardiovasc Dis. 2010;20(5):317–325. doi:10.1016/j.numecd.2009.04.007.19570664
121 Teng KT, Chang LF, Vethakkan SR, Nesaretnam K, Sanders TAB. Effects of exchanging carbohydrate or monounsaturated fat with saturated fat on inflammatory and thrombogenic responses in subjects with abdominal obesity: a randomized controlled trial. Clin Nutr. 2017;36(5):1250–1258. doi:10.1016/j.clnu.2016.08.026.27642057
122 Teng KT, Voon PT, Cheng HM, Nesaretnam K. Effects of partially hydrogenated, semi-saturated, and high oleate vegetable oils on inflammatory markers and lipids. Lipids. 2010;45(5):385–392. doi:10.1007/s11745-010-3416-1.20437207
123 Thompson HJ, Sedlacek SM, Paul D, . Effect of dietary patterns differing in carbohydrate and fat content on blood lipid and glucose profiles based on weight-loss success of breast-cancer survivors. Breast Cancer Res. 2012;14(1):R1. doi:10.1186/bcr3082.22225711
124 Tindall AM, Petersen KS, Skulas-Ray AC, Richter CK, Proctor DN, Kris-Etherton PM. Replacing saturated fat with walnuts or vegetable oils improves central blood pressure and serum lipids in adults at risk for cardiovascular disease: a randomized controlled-feeding trial. J Am Heart Assoc. 2019;8(9):e011512. doi:10.1161/jaha.118.011512.31039663
125 Utzschneider KM, Bayer-Carter JL, Arbuckle MD, Tidwell JM, Richards TL, Craft S. Beneficial effect of a weight-stable, low-fat/low-saturated fat/low-glycaemic index diet to reduce liver fat in older subjects. Br J Nutr. 2013;109(6):1096–1104. doi:10.1017/s0007114512002966.22849970
126 Vafeiadou K, Weech M, Altowaijri H, . Replacement of saturated with unsaturated fats had no impact on vascular function but beneficial effects on lipid biomarkers, E-selectin, and blood pressure: results from the randomized, controlled Dietary Intervention and VAScular function (DIVAS) study. Am J Clin Nutr. 2015;102(1):40–48. doi:10.3945/ajcn.114.097089.26016869
127 van der Made SM, Kelly ER, Berendschot TT, Kijlstra A, Lutjohann D, Plat J. Consuming a buttermilk drink containing lutein-enriched egg yolk daily for 1 year increased plasma lutein but did not affect serum lipid or lipoprotein concentrations in adults with early signs of age-related macular degeneration. J Nutr. 2014;144(9):1370–1377. doi:10.3945/jn.114.195503.24991045
128 van Meijl LE, Mensink RP. Low-fat dairy consumption reduces systolic blood pressure, but does not improve other metabolic risk parameters in overweight and obese subjects. Nutr Metab Cardiovasc Dis. 2011;21(5):355–361. doi:10.1016/j.numecd.2009.10.008.20153619
129 Varady KA, Bhutani S, Klempel MC, Phillips SA. Improvements in vascular health by a low-fat diet, but not a high-fat diet, are mediated by changes in adipocyte biology. Nutr J. 2011;10:8. doi:10.1186/1475-2891-10-8.21251283
130 Veum VL, Laupsa-Borge J, Eng O, . Visceral adiposity and metabolic syndrome after very high-fat and low-fat isocaloric diets: a randomized controlled trial. Am J Clin Nutr. 2017;105(1):85–99. doi:10.3945/ajcn.115.123463.27903520
131 Wang L, Bordi PL, Fleming JA, Hill AM, Kris-Etherton PM. Effect of a moderate fat diet with and without avocados on lipoprotein particle number, size and subclasses in overweight and obese adults: a randomized, controlled trial. J Am Heart Assoc. 2015;4(1):e001355. doi:10.1161/jaha.114.001355.25567051
132 Werner LB, Hellgren LI, Raff M, . Effects of butter from mountain-pasture grazing cows on risk markers of the metabolic syndrome compared with conventional Danish butter: a randomized controlled study. Lipids Health Dis. 2013;12:99. doi:10.1186/1476-511x-12-99.23842081
133 Young AJ, Marriott BP, Champagne CM, . Blood fatty acid changes in healthy young Americans in response to a 10-week diet that increased n-3 and reduced n-6 fatty acid consumption: a randomised controlled trial. Br J Nutr. 2017;117(9):1257–1269. doi:10.1017/s0007114517001003.28534446
134 Yubero-Serrano EM, Delgado-Lista J, Tierney AC, . Insulin resistance determines a differential response to changes in dietary fat modification on metabolic syndrome risk factors: the LIPGENE study. Am J Clin Nutr. 2015;102(6):1509–1517. doi:10.3945/ajcn.115.111286.26561628
135 Abdollahi AM, Virtanen HEK, Voutilainen S, . Egg consumption, cholesterol intake, and risk of incident stroke in men: the Kuopio Ischaemic Heart Disease Risk Factor Study. Am J Clin Nutr. 2019;110(1):169–176. doi:10.1093/ajcn/nqz066.31095282
136 Akbaraly TN, Ferrie JE, Berr C, . Alternative Healthy Eating Index and mortality over 18 y of follow-up: results from the Whitehall II cohort. Am J Clin Nutr. 2011;94(1):247–253. doi:10.3945/ajcn.111.013128.21613557
137 Akesson A, Donat-Vargas C, Berglund M, Glynn A, Wolk A, Kippler M. Dietary exposure to polychlorinated biphenyls and risk of heart failure - a population-based prospective cohort study. Environ Int. 2019;126:1–6. doi:10.1016/j.envint.2019.01.069.30776745
138 Amiano P, Machon M, Dorronsoro M, . Intake of total omega-3 fatty acids, eicosapentaenoic acid and docosahexaenoic acid and risk of coronary heart disease in the Spanish EPIC cohort study. Nutr Metab Cardiovasc Dis. 2014;24(3):321–327. doi:10.1016/j.numecd.2013.08.011.24360762
139 Atkinson C, Whitley E, Ness A, Baker I. Associations between types of dietary fat and fish intake and risk of stroke in the Caerphilly Prospective Study (CaPS). Public Health. 2011;125(6):345–348. doi:10.1016/j.puhe.2011.03.002.21636104
140 Belin RJ, Greenland P, Allison M, . Diet quality and the risk of cardiovascular disease: the Women’s Health Initiative (WHI). Am J Clin Nutr. 2011;94(1):49–57. doi:10.3945/ajcn.110.011221.21613562
141 Belin RJ, Greenland P, Martin L, . Fish intake and the risk of incident heart failure: the Women’s Health Initiative. Circ Heart Fail. 2011;4(4):404–413. doi:10.1161/circheartfailure.110.960450.21610249
142 Bell GA, Kantor ED, Lampe JW, Kristal AR, Heckbert SR, White E. Intake of long-chain omega-3 fatty acids from diet and supplements in relation to mortality. Am J Epidemiol. 2014;179(6):710–720. doi:10.1093/aje/kwt326.24496442
143 Bendinelli B, Masala G, Saieva C, . Fruit, vegetables, and olive oil and risk of coronary heart disease in Italian women: the EPICOR Study. Am J Clin Nutr. 2011;93(2):275–283. doi:10.3945/ajcn.110.000521.21177799
144 Bergkvist C, Berglund M, Glynn A, Julin B, Wolk A, Akesson A. Dietary exposure to polychlorinated biphenyls and risk of myocardial infarction in men - a population-based prospective cohort study. Environ Int. 2016;88:9–14. doi:10.1016/j.envint.2015.11.020.26690540
145 Bergkvist C, Berglund M, Glynn A, Wolk A, Akesson A. Dietary exposure to polychlorinated biphenyls and risk of myocardial infarction - a population-based prospective cohort study. Int J Cardiol. 2015;183:242–248. doi:10.1016/j.ijcard.2015.01.055.25679993
146 Bergkvist C, Kippler M, Larsson SC, . Dietary exposure to polychlorinated biphenyls is associated with increased risk of stroke in women. J Intern Med. 2014;276(3):248–259. doi:10.1111/joim.12194.24428778
147 Blekkenhorst LC, Prince RL, Hodgson JM, . Dietary saturated fat intake and atherosclerotic vascular disease mortality in elderly women: a prospective cohort study. Am J Clin Nutr. 2015;101(6):1263–1268. doi:10.3945/ajcn.114.102392.25948671
148 Bork CS, Jakobsen MU, Lundbye-Christensen S, Tjonneland A, Schmidt EB, Overvad K. Dietary intake and adipose tissue content of alpha-linolenic acid and risk of myocardial infarction: a Danish cohort study. Am J Clin Nutr. 2016;104(1):41–48. doi:10.3945/ajcn.115.127019.27169831
149 Bork CS, Veno SK, Lundbye-Christensen S, . Dietary intake of alpha-linolenic acid is not appreciably associated with risk of ischemic stroke among middle-aged Danish men and women. J Nutr. 2018;148(6):952–958. doi:10.1093/jn/nxy056.29767732
150 Buckland G, Mayen AL, Agudo A, . Olive oil intake and mortality within the Spanish population (EPIC-Spain). Am J Clin Nutr. 2012;96(1):142–149. doi:10.3945/ajcn.111.024216.22648725
151 Buckland G, Travier N, Barricarte A, . Olive oil intake and CHD in the European Prospective Investigation into Cancer and Nutrition Spanish cohort. Br J Nutr. 2012;108(11):2075–2082. doi:10.1017/s000711451200298x.23006416
152 Chiuve SE, Rimm EB, Sandhu RK, . Dietary fat quality and risk of sudden cardiac death in women. Am J Clin Nutr. 2012;96(3):498–507. doi:10.3945/ajcn.112.040287.22854398
153 de Goede J, Geleijnse JM, Boer JM, Kromhout D, Verschuren WM. Marine (n-3) fatty acids, fish consumption, and the 10-year risk of fatal and nonfatal coronary heart disease in a large population of Dutch adults with low fish intake. J Nutr. 2010;140(5):1023–1028. doi:10.3945/jn.109.119271.20335635
154 de Goede J, Geleijnse JM, Boer JM, Kromhout D, Verschuren WM. Linoleic acid intake, plasma cholesterol and 10-year incidence of CHD in 20,000 middle-aged men and women in the Netherlands. Br J Nutr. 2012;107(7):1070–1076. doi:10.1017/s0007114511003837.21816117
155 de Goede J, Verschuren WM, Boer JM, Kromhout D, Geleijnse JM. Alpha-linolenic acid intake and 10-year incidence of coronary heart disease and stroke in 20,000 middle-aged men and women in the Netherlands. PLoS One. 2011;6(3):e17967. doi:10.1371/journal.pone.0017967.21464993
156 de Oliveira Otto MC, Mozaffarian D, Kromhout D, . Dietary intake of saturated fat by food source and incident cardiovascular disease: the Multi-Ethnic Study of Atherosclerosis. Am J Clin Nutr. 2012;96(2):397–404. doi:10.3945/ajcn.112.037770.22760560
157 de Oliveira Otto MC, Wu JH, Baylin A, . Circulating and dietary omega-3 and omega-6 polyunsaturated fatty acids and incidence of CVD in the Multi-Ethnic Study of Atherosclerosis. J Am Heart Assoc. 2013;2(6):e000506. doi:10.1161/jaha.113.000506.24351702
158 Donat-Vargas C, Bellavia A, Berglund M, Glynn A, Wolk A, Akesson A. Cardiovascular and cancer mortality in relation to dietary polychlorinated biphenyls and marine polyunsaturated fatty acids: a nutritional-toxicological aspect of fish consumption. J Intern Med. 2020;287(2):197–209. doi:10.1111/joim.12995.31628875
159 Fretts AM, Mozaffarian D, Siscovick DS, . Plasma phospholipid and dietary alpha-linolenic acid, mortality, CHD and stroke: the Cardiovascular Health Study. Br J Nutr. 2014;112(7):1206–1213. doi:10.1017/s0007114514001925.25159901
160 Gammelmark A, Nielsen MS, Bork CS, . Association of fish consumption and dietary intake of marine n-3 PUFA with myocardial infarction in a prospective Danish cohort study. Br J Nutr. 2016;116(1):167–177. doi:10.1017/s000711451600180x.27189437
161 Gardener H, Wright CB, Gu Y, . Mediterranean-style diet and risk of ischemic stroke, myocardial infarction, and vascular death: the Northern Manhattan Study. Am J Clin Nutr. 2011;94(6):1458–1464. doi:10.3945/ajcn.111.012799.22071704
162 Goldbohm RA, Chorus AM, Galindo Garre F, Schouten LJ, van den Brandt PA. Dairy consumption and 10-y total and cardiovascular mortality: a prospective cohort study in the Netherlands. Am J Clin Nutr. 2011;93(3):615–627. doi:10.3945/ajcn.110.000430.21270377
163 Guasch-Ferre M, Babio N, Martinez-Gonzalez MA, . Dietary fat intake and risk of cardiovascular disease and all-cause mortality in a population at high risk of cardiovascular disease. Am J Clin Nutr. 2015;102(6):1563–1573. doi:10.3945/ajcn.115.116046.26561617
164 Guasch-Ferre M, Hu FB, Martinez-Gonzalez MA, . Olive oil intake and risk of cardiovascular disease and mortality in the PREDIMED Study. BMC Med. 2014;12:78. doi:10.1186/1741-7015-12-78.24886626
165 Hellstrand S, Ericson U, Gullberg B, Hedblad B, Orho-Melander M, Sonestedt E. Genetic variation in FADS1 has little effect on the association between dietary PUFA intake and cardiovascular disease. J Nutr. 2014;144(9):1356–1363. doi:10.3945/jn.114.192708.25008580
166 Hisamatsu T, Miura K, Ohkubo T, . Interaction between dietary marine-derived n-3 fatty acids intake and J-point elevation on the risk of cardiac death: a 24-year follow-up of Japanese men. Heart. 2013;99(14):1024–1029. doi:10.1136/heartjnl-2012-303496.23666393
167 Hlebowicz J, Drake I, Gullberg B, . A high diet quality is associated with lower incidence of cardiovascular events in the Malmo diet and cancer cohort. PLoS One. 2013;8(8):e71095. doi:10.1371/journal.pone.0071095.23940694
168 Houston DK, Ding J, Lee JS, . Dietary fat and cholesterol and risk of cardiovascular disease in older adults: the Health ABC Study. Nutr Metab Cardiovasc Dis. 2011;21(6):430–437. doi:10.1016/j.numecd.2009.11.007.20338738
169 Isaksen T, Evensen LH, Johnsen SH, . Dietary intake of marine n-3 polyunsaturated fatty acids and future risk of venous thromboembolism. Res Pract Thromb Haemost. 2019;3(1):59–69. doi:10.1002/rth2.12168.30656277
170 Jakobsen MU, Dethlefsen C, Joensen AM, . Intake of carbohydrates compared with intake of saturated fatty acids and risk of myocardial infarction: importance of the glycemic index. Am J Clin Nutr. 2010;91(6):1764–1768. doi:10.3945/ajcn.2009.29099.20375186
171 Joensen AM, Schmidt EB, Dethlefsen C, . Dietary intake of total marine n-3 polyunsaturated fatty acids, eicosapentaenoic acid, docosahexaenoic acid and docosapentaenoic acid and the risk of acute coronary syndrome - a cohort study. Br J Nutr. 2010;103(4):602–607. doi:10.1017/s0007114509992170.19825219
172 Juan J, Huang H, Jiang X, . Joint effects of fatty acid desaturase 1 polymorphisms and dietary polyunsaturated fatty acid intake on circulating fatty acid proportions. Am J Clin Nutr. 2018;107(5):826–833. doi:10.1093/ajcn/nqy025.29722844
173 Kiage JN, Sampson UK, Lipworth L, . Intake of polyunsaturated fat in relation to mortality among statin users and non-users in the Southern Community Cohort Study. Nutr Metab Cardiovasc Dis. 2015;25(11):1016–1024. doi:10.1016/j.numecd.2015.07.006.26298428
174 Kippler M, Larsson SC, Berglund M, Glynn A, Wolk A, Akesson A. Associations of dietary polychlorinated biphenyls and long-chain omega-3 fatty acids with stroke risk. Environ Int. 2016;94:706–711. doi:10.1016/j.envint.2016.07.012.27473885
175 Koh AS, Pan A, Wang R, . The association between dietary omega-3 fatty acids and cardiovascular death: the Singapore Chinese Health Study. Eur J Prev Cardiol. 2015;22(3):364–372. doi:10.1177/2047487313517576.24343844
176 Koskinen TT, Virtanen HEK, Voutilainen S, Tuomainen TP, Mursu J, Virtanen JK. Intake of fermented and non-fermented dairy products and risk of incident CHD: the Kuopio Ischaemic Heart Disease Risk Factor Study. Br J Nutr. 2018;120(11):1288–1297. doi:10.1017/s0007114518002830.30370878
177 Kouli GM, Panagiotakos DB, Kyrou I, . Olive oil consumption and 10-year (2002-2012) cardiovascular disease incidence: the ATTICA study. Eur J Nutr. 2019;58(1):131–138. doi:10.1007/s00394-017-1577-x.29124386
178 Kulezic A, Bergwall S, Fatemi S, . Healthy diet and fiber intake are associated with decreased risk of incident symptomatic peripheral artery disease - a prospective cohort study. Vasc Med. 2019;24(6):511–518. doi:10.1177/1358863x19867393.31431146
179 Larsson SC, Virtamo J, Wolk A. Dietary fats and dietary cholesterol and risk of stroke in women. Atherosclerosis. 2012;221(1):282–286. doi:10.1016/j.atherosclerosis.2011.12.043.22265275
180 Lemaitre RN, Sitlani C, Song X, . Circulating and dietary alpha-linolenic acid and incidence of congestive heart failure in older adults: the Cardiovascular Health Study. Am J Clin Nutr. 2012;96(2):269–274. doi:10.3945/ajcn.112.037960.22743310
181 Levitan EB, Wolk A, Hakansson N, Mittleman MA. α-Linolenic acid, linoleic acid and heart failure in women. Br J Nutr. 2012;108(7):1300–1306. doi:10.1017/s0007114511006726.22172525
182 Levitan EB, Wolk A, Mittleman MA. Fatty fish, marine omega-3 fatty acids and incidence of heart failure. Eur J Clin Nutr. 2010;64(6):587–594. doi:10.1038/ejcn.2010.50.20332801
183 Li Y, Hruby A, Bernstein AM, . Saturated fats compared with unsaturated fats and sources of carbohydrates in relation to risk of coronary heart disease: a prospective cohort study. J Am Coll Cardiol. 2015;66(14):1538–1548. doi:10.1016/j.jacc.2015.07.055.26429077
184 Lin HP, Baghdasarian S, Singer MR, . Dietary cholesterol, lipid levels, and cardiovascular risk among adults with diabetes or impaired fasting glucose in the Framingham Offspring Study. Nutrients. 2018;10(6). doi:10.3390/nu10060770.
185 Miyagawa N, Miura K, Okuda N, . Long-chain n-3 polyunsaturated fatty acids intake and cardiovascular disease mortality risk in Japanese: a 24-year follow-up of NIPPON DATA80. Atherosclerosis. 2014;232(2):384–389. doi:10.1016/j.atherosclerosis.2013.11.073.24468152
186 Nagata C, Nakamura K, Wada K, . Total fat intake is associated with decreased mortality in Japanese men but not in women. J Nutr. 2012;142(9):1713–1719. doi:10.3945/jn.112.161661.22810986
187 Nakamura Y, Kiyohara Y, Okuda N, . Fatty acid intakes and coronary heart disease mortality in Japan: NIPPON DATA90, 1990-2005. Curr Nutr Food Sci. 2013;9(1):26–32. doi:10.2174/1573401311309010006.
188 Neelakantan N, Koh WP, Yuan JM, van Dam RM. Diet-Quality Indexes are associated with a lower risk of cardiovascular, respiratory, and all-cause mortality among Chinese adults. J Nutr. 2018;148(8):1323–1332. doi:10.1093/jn/nxy094.29982724
189 Neelakantan N, Naidoo N, Koh WP, Yuan JM, van Dam RM. The Alternative Healthy Eating Index is associated with a lower risk of fatal and nonfatal acute myocardial infarction in a Chinese Adult population. J Nutr. 2016;146(7):1379–1386. doi:10.3945/jn.116.231605.27306893
190 Okada C, Imano H, Yamagishi K, . Dietary intake of energy and nutrients from breakfast and risk of stroke in the Japanese population: the Circulatory Risk in Communities Study (CIRCS). J Atheroscler Thromb. 2019;26(2):145–153. doi:10.5551/jat.44438.29899172
191 O’Neil A, Shivappa N, Jacka FN, . Pro-inflammatory dietary intake as a risk factor for CVD in men: a 5-year longitudinal study. Br J Nutr. 2015;114(12):2074–2082. doi:10.1017/s0007114515003815.26450630
192 Owen AJ, Magliano DJ, O’Dea K, Barr EL, Shaw JE. Polyunsaturated fatty acid intake and risk of cardiovascular mortality in a low fish-consuming population: a prospective cohort analysis. Eur J Nutr. 2016;55(4):1605–1613. doi:10.1007/s00394-015-0979-x.26201872
193 Pala V, Sieri S, Chiodini P, . Associations of dairy product consumption with mortality in the European Prospective Investigation into Cancer and Nutrition (EPIC)-Italy cohort. Am J Clin Nutr. 2019;110(5):1220–1230. doi:10.1093/ajcn/nqz183.31435641
194 Patterson E, Larsson SC, Wolk A, Akesson A. Association between dairy food consumption and risk of myocardial infarction in women differs by type of dairy food. J Nutr. 2013;143(1):74–79. doi:10.3945/jn.112.166330.23173172
195 Pierucci P, Misciagna G, Ventura MT, . Diet and myocardial infarction: a nested case-control study in a cohort of elderly subjects in a Mediterranean area of southern Italy. Nutr Metab Cardiovasc Dis. 2012;22(9):727–733. doi:10.1016/j.numecd.2010.12.002.21482083
196 Praagman J, Beulens JW, Alssema M, . The association between dietary saturated fatty acids and ischemic heart disease depends on the type and source of fatty acid in the European Prospective Investigation into Cancer and Nutrition-Netherlands cohort. Am J Clin Nutr. 2016;103(2):356–365. doi:10.3945/ajcn.115.122671.26791181
197 Praagman J, de Jonge EA, Kiefte-de Jong JC, . Dietary saturated fatty acids and coronary heart disease risk in a Dutch middle-aged and elderly population. Arterioscler Thromb Vasc Biol. 2016;36(9):2011–2018. doi:10.1161/atvbaha.116.307578.27417581
198 Praagman J, Vissers LET, Mulligan AA, . Consumption of individual saturated fatty acids and the risk of myocardial infarction in a UK and a Danish cohort. Int J Cardiol. 2019;279:18–26. doi:10.1016/j.ijcard.2018.10.064.30482628
199 Reedy J, Krebs-Smith SM, Miller PE, . Higher diet quality is associated with decreased risk of all-cause, cardiovascular disease, and cancer mortality among older adults. J Nutr. 2014;144(6):881–889. doi:10.3945/jn.113.189407.24572039
200 Rhee JJ, Kim E, Buring JE, Kurth T. Fish consumption, omega-3 fatty acids, and risk of cardiovascular disease. Am J Prev Med. 2017;52(1):10–19. doi:10.1016/j.amepre.2016.07.020.27646568
201 Ricci C, Baumgartner J, Zec M, Kruger HS, Smuts CM. Type of dietary fat intakes in relation to all-cause and cause-specific mortality in US adults: an iso-energetic substitution analysis from the American National Health and Nutrition Examination Survey linked to the US mortality registry. Br J Nutr. 2018;119(4):456–463. doi:10.1017/s0007114517003889.29498349
202 Sala-Vila A, Guasch-Ferre M, Hu FB, . Dietary alpha-linolenic acid, marine omega-3 fatty acids, and mortality in a population with high fish consumption: findings from the PREvencion con DIeta MEDiterranea (PREDIMED) Study. J Am Heart Assoc. 2016;5(1). doi:10.1161/jaha.115.002543.
203 Samieri C, Feart C, Proust-Lima C, . Olive oil consumption, plasma oleic acid, and stroke incidence: the Three-City Study. Neurology. 2011;77(5):418–425. doi:10.1212/WNL.0b013e318220abeb.21676914
204 Santiago S, Zazpe I, Gea A, . Fat quality index and risk of cardiovascular disease in the Sun Project. J Nutr Health Aging. 2018;22(4):526–533. doi:10.1007/s12603-018-1003-y.29582893
205 Simila ME, Kontto JP, Mannisto S, Valsta LM, Virtamo J. Glycaemic index, carbohydrate substitution for fat and risk of CHD in men. Br J Nutr. 2013;110(9):1704–1711. doi:10.1017/s0007114513000858.23534456
206 Sonestedt E, Wirfalt E, Wallstrom P, Gullberg B, Orho-Melander M, Hedblad B. Dairy products and its association with incidence of cardiovascular disease: the Malmo diet and cancer cohort. Eur J Epidemiol. 2011;26(8):609–618. doi:10.1007/s10654-011-9589-y.21660519
207 Stefler D, Malyutina S, Kubinova R, . Mediterranean diet score and total and cardiovascular mortality in Eastern Europe: the HAPIEE study. Eur J Nutr. 2017;56(1):421–429. doi:10.1007/s00394-015-1092-x.26578528
208 Strom M, Halldorsson TI, Mortensen EL, Torp-Pedersen C, Olsen SF. Fish, n-3 fatty acids, and cardiovascular diseases in women of reproductive age: a prospective study in a large national cohort. Hypertension. 2012;59(1):36–43. doi:10.1161/hypertensionaha.111.179382.22146511
209 Sun Y, Koh WP, Yuan JM, . Plasma alpha-linolenic and long-chain omega-3 fatty acids are associated with a lower risk of acute myocardial infarction in Singapore Chinese adults. J Nutr. 2016;146(2):275–282. doi:10.3945/jn.115.220418.26609174
210 Vedtofte MS, Jakobsen MU, Lauritzen L, Heitmann BL. Dietary alpha-linolenic acid, linoleic acid, and n-3 long-chain PUFA and risk of ischemic heart disease. Am J Clin Nutr. 2011;94(4):1097–1103. doi:10.3945/ajcn.111.018762.21865326
211 Veno SK, Bork CS, Jakobsen MU, . Marine n-3 polyunsaturated fatty acids and the risk of ischemic stroke. Stroke. 2019;50(2):274–282. doi:10.1161/strokeaha.118.023384.30602356
212 Veno SK, Schmidt EB, Jakobsen MU, Lundbye-Christensen S, Bach FW, Overvad K. Substitution of linoleic acid for other macronutrients and the risk of ischemic stroke. Stroke. 2017;48(12):3190–3195. doi:10.1161/strokeaha.117.017935.29070717
213 Virtanen JK, Mursu J, Tuomainen TP, Voutilainen S. Dietary fatty acids and risk of coronary heart disease in men: the Kuopio Ischemic Heart Disease Risk Factor Study. Arterioscler Thromb Vasc Biol. 2014;34(12):2679–2687. doi:10.1161/atvbaha.114.304082.25256234
214 Virtanen JK, Mursu J, Virtanen HE, . Associations of egg and cholesterol intakes with carotid intima-media thickness and risk of incident coronary artery disease according to apolipoprotein E phenotype in men: the Kuopio Ischaemic Heart Disease Risk Factor Study. Am J Clin Nutr. 2016;103(3):895–901. doi:10.3945/ajcn.115.122317.26864369
215 Vissers LET, Rijksen J, Boer JMA, Verschuren WMM, van der Schouw YT, Sluijs I. Fatty acids from dairy and meat and their association with risk of coronary heart disease. Eur J Nutr. 2019;58(7):2639–2647. doi:10.1007/s00394-018-1811-1.30167851
216 Wakai K, Naito M, Date C, Iso H, Tamakoshi A. Dietary intakes of fat and total mortality among Japanese populations with a low fat intake: The Japan Collaborative Cohort (JACC) Study. Nutr Metab (Lond). 2014;11(1):12. doi:10.1186/1743-7075-11-12.24597664
217 Wallstrom P, Sonestedt E, Hlebowicz J, . Dietary fiber and saturated fat intake associations with cardiovascular disease differ by sex in the Malmo Diet and Cancer Cohort: a prospective study. PLoS One. 2012;7(2):e31637. doi:10.1371/journal.pone.0031637.22384046
218 Wang DD, Li Y, Chiuve SE, . Association of specific dietary fats with total and cause-specific mortality. JAMA Intern Med. 2016;176(8):1134–1145. doi:10.1001/jamainternmed.2016.2417.27379574
219 Wilk JB, Tsai MY, Hanson NQ, Gaziano JM, Djousse L. Plasma and dietary omega-3 fatty acids, fish intake, and heart failure risk in the Physicians’ Health Study. Am J Clin Nutr. 2012;96(4):882–888. doi:10.3945/ajcn.112.042671.22952185
220 Yaemsiri S, Sen S, Tinker L, Rosamond W, Wassertheil-Smoller S, He K. Trans fat, aspirin, and ischemic stroke in postmenopausal women. Ann Neurol. 2012;72(5):704–715. doi:10.1002/ana.23555.22383309
221 Yamagishi K, Iso H, Kokubo Y, . Dietary intake of saturated fatty acids and incident stroke and coronary heart disease in Japanese communities: The JPHC Study. Eur Heart J. 2013;34(16):1225–1232. doi:10.1093/eurheartj/eht043.23404536
222 Yamagishi K, Iso H, Yatsuya H, . Dietary intake of saturated fatty acids and mortality from cardiovascular disease in Japanese: The Japan Collaborative Cohort Study for Evaluation of Cancer Risk (JACC) Study. Am J Clin Nutr. 2010;92(4):759–765. doi:10.3945/ajcn.2009.29146.20685950
223 Zhang Y, Zhuang P, He W, . Association of fish and long-chain omega-3 fatty acids intakes with total and cause-specific mortality: prospective analysis of 421 309 individuals. J Intern Med. 2018;284(4):399–417. doi:10.1111/joim.12786.30019399
224 Zhong VW, Van Horn L, Cornelis MC, . Associations of dietary cholesterol or egg consumption with incident cardiovascular disease and mortality. JAMA. 2019;321(11):1081–1095. doi:10.1001/jama.2019.1572.30874756
225 Zhuang P, Wang W, Wang J, Zhang Y, Jiao J. Polyunsaturated fatty acids intake, omega-6/omega-3 ratio and mortality: findings from two independent nationwide cohorts. Clin Nutr. 2019;38(2):848–855. doi:10.1016/j.clnu.2018.02.019.29551407
226 Zhuang P, Zhang Y, He W, . Dietary fats in relation to total and cause-specific mortality in a prospective cohort of 521,120 individuals with 16 years of follow-up. Circ Res. 2019;124(5):757–768. doi:10.1161/circresaha.118.314038.30636521
227 Zong G, Li Y, Sampson L, . Monounsaturated fats from plant and animal sources in relation to risk of coronary heart disease among US men and women. Am J Clin Nutr. 2018;107(3):445–453. doi:10.1093/ajcn/nqx004.29566185
228 Zong G, Li Y, Wanders AJ, . Intake of individual saturated fatty acids and risk of coronary heart disease in US men and women: two prospective longitudinal cohort studies. BMJ. 2016;355:i5796. doi:10.1136/bmj.i5796.27881409

Table 1 Evidence from randomized controlled trials examining types of dietary fat consumed during childhood and cardiovascular disease intermediate and endpoint outcomes^*^

Study and Population Characteristics | Interventions, Comparators, Outcomes | Results^†^ | Model Adjustments, Limitations
RCT: Parallel Design
Dietary Intervention Study in Children (DISC)
Kwiterovich, 1995 (https://www.ncbi.nlm.nih.gov/pubmed/7723156) ^13^; RCT, DISC, U.S.; Baseline N=663 Analytic N=623 (Attrition: 6%); Participant characteristics at baseline:; - Children with LDL at the 80^th^ – 98^th^ percentile for age and sex at study entry; - Age: Boys, Mean=9.7y; Girls, Mean=9.0y; - Sex (female): 45%; - Race/ethnicity: White ~86.5%, Black ~8.5%, Other ~5.0%; - SES: NR; - Anthropometry: BMI, Mean~17.5; Blood lipids at baseline, Mean:; - TC (mmol/L): ~5.17; - LDL (mmol/L): ~3.38; - HDL (mmol/L): ~1.48; - Triglycerides (mmol/L): ~0.90; - No baseline differences between intervention and control group at baseline; Summary of findings:; In children with elevated LDL cholesterol, counseling to adhere to a diet providing less than 8% energy from SFA, up to 9% energy from PUFA, and less than 75mg/kcal of cholesterol, compared to usual care, reduced total and LDL cholesterol, but not HDL cholesterol or triglycerides, after 3y of follow-up. | Interventions/Comparators:; - [underlined: Intervention] (n=320): Counseling to adhere to a diet providing less than 8% energy from SFA, up to 9% energy from PUFA, less than 75mg/1000kcal of cholesterol, and 28%E from total fat.; - [underlined: Control] (n=303): Usual care; [underlined: Intervention duration]: 3 years (Intervention group: 6 weekly and 5 biweekly sessions during 1^st^ 6mo; 6 sessions during 2^nd^ 6mo; 4-6 sessions during 2^nd^ and 3^rd^ years); [underlined: Intervention compliance]: Fat intake measured at 1y and 3y follow-up via multiple 24hr recalls, Mean (SD) for intervention vs control:; - SFA (%E): 1y, 9.8 (2.7) vs 12.4 (2.6), p<0.001; 3y, 10.2 (2.6) vs 12.3 (2.2), p<0.001; - MUFA (%E): 1y, 10.7 (2.5) vs 12.3 (2.4), p<0.001; 3y, 10.7 (2.5) vs 12.3 (2.1), p<0.001; - PUFA (%E): 1y, 5.8 (1.8) vs 5.9 (1.9), p=0.88; 3y, 5.5 (1.9) vs 5.9 (1.8), p=0.03; - Cholesterol (mg/1000kcal): 1y, 90.0 (42.6) vs 113.9 (51.9), p<0.001; 3y, 95.0 (47.8) vs 112.9 (48.0), p<0.001; Outcomes and assessment methods:; - Assessed at baseline (~9.5y), 1y, and 3y follow-ups; - [underlined: Blood lipids:] TC, LDL, HDL, triglycerides (NR if fasting or non-fasting) | Blood lipids at 1y, 3y follow-up; [underlined: TC,] mmol/L, Mean (SD); Intervention: 4.95 (0.54), 4.74 (0.56); Control (ref): 5.10 (0.55), 4.82 (0.58); Group differences, Mean (95% CI):; 1y F/U: −0.16 (−0.23, −0.08), p<0.001; 3y F/U: −0.08 (−0.17, −0.004), p=0.04; [underlined: LDL,] mmol/L, Mean (SD); Intervention: 3.17 (0.47), 2.98 (0.48); Control (ref): 3.29 (0.50), 3.07 (0.50); Group differences, Mean (95% CI):; 1y F/U: −0.13 (−0.19, −0.06), p<0.001; 3y F/U: −0.09 (−0.16, −0.02), p=0.02; Group differences in [underlined: change]: Greater decrease in LDL in the intervention group from baseline to 1y (p<0.001) and to 3y (p<0.05) compared to control; [underlined: HDL,] mmol/L, Mean (SD); Intervention: 1.44 (0.29), 1.36 (0.26); Control (ref): 1.47 (0.29), 1.36 (0.27); Group differences, Mean (95% CI):; 1y F/U: −0.03 (−0.06, −0.004), p=0.03; 3y F/U: −0.005 (−0.03, 0.02), p=0.75; [underlined: Triglycerides,] mmol/L, Mean (SD); Intervention: 0.97 (0.44), 1.12 (0.52); Control (ref): 0.98 (0.44), 1.12 (0.51); Group differences, Mean (95% CI):; 1y F/U: −0.01 (−0.07, 0.05), p=0.84; 3y F/U: 0.02 (−0.05, 0.08), p=0.62 | Model adjustments:; Baseline blood lipid level, sex; Limitations:; - Although dietary fats was the focus of the intervention, increased dietary fiber with an emphasis on fruits, vegetables, and whole grains was also encouraged; - None to report; Funding sources:; NHLBI
Simons-Morton, 1997 (https://www.ncbi.nlm.nih.gov/pubmed/9095079) ^32^; RCT, DISC, U.S.; Baseline N=663 Analytic N=583 (Attrition: 12%); Participant characteristics at baseline:; - Children with LDL cholesterol values at the 80^th^ – 98^th^ percentile for age and sex at study entry; - Age: Mean=9.6y, SD=0.72; - Sex (female): 46%; - Race/ethnicity: White ~86.5%, Black ~8.5%, Other ~5.0%; - SES: NR; - Anthropometry: Height, Mean=136.4 cm, SD=6.9; Weight, Mean=32.9 kg, SD=6.8; BP at baseline, Mean:; - SBP (mmHg): ~97.4; - DBP (mmHg): ~61.9; - No statistically significant differences between intervention and control groups at baseline; Summary of findings:; In children with elevated LDL cholesterol, counseling to adhere to a diet providing less than 8% energy from SFA, up to 9% energy from PUFA, and less than 75mg/kcal of cholesterol, compared to usual care, did not reduce SBP or DBP after 3y of follow-up. | Interventions/Comparators:; - [underlined: Intervention] (n=302): Counseling to adhere to a diet providing less than 8% energy from SFA, up to 9% energy from PUFA, less than 75mg/1000kcal of cholesterol, and 28% energy from total fat.; - [underlined: Control] (n=281): Usual care; [underlined: Intervention duration]: 3 years (Intervention group: 6 weekly and 5 biweekly sessions during 1^st^ 6mo; 6 sessions during 2^nd^ 6mo; 4-6 sessions during 2^nd^ and 3^rd^ years); [underlined: Intervention compliance]: DISC intervention significantly reduced total fat, saturated fat, and cholesterol intake compared to usual care (See Kwiterovich, 1995); Outcomes and assessment methods:; - Assessed at baseline (~9.6y), 1y, and 3y follow-ups; - [underlined: BP:] SBP, DBP; Measured in duplicate | BP at 1y, 3y follow-up; [underlined: SBP,] mmHg, Mean (SD); Intervention: 96.9 (8.2), 100.0 (9.1); Control (ref): 97.3 (8.3), 100.4 (8.6); Group differences, Mean (95% CI):; 1y F/U: −0.4 (−1.51, 0.69), p=0.47; 3y F/U: −0.5 (−1.69, 0.78), p=0.47; [underlined: DBP,] mmHg, Mean (SD); Intervention: 60.5 (9.2), 63.4 (9.1); Control (ref): 61.0 (9.9), 64.3 (8.1); Group differences, Mean (95% CI):; 1y F/U: −0.6 (1.94, 0.80), p=0.42; 3y F/U: −1.0 (−2.35, 0.38), p=0.16 | Model adjustments:; Baseline BP, sex; Limitations:; - Although dietary fats was the focus of the intervention, increased dietary fiber with an emphasis on fruits, vegetables, and whole grains was also encouraged; - No preregistered statistical analysis plan for SBP and DBP available; Funding sources:; NHLBI
Obarzanek, 2001 (https://www.ncbi.nlm.nih.gov/pubmed/11158455) ^25^; RCT, DISC, U.S.; Baseline N=663 Analytic N=548 (Attrition: 17%); Participant characteristics at baseline:; - Children with LDL cholesterol values at the 80^th^ – 98^th^ percentile for age and sex at study entry; - Age: Mean=9.5y, SD=0.72y; - Sex (female): 45%; - Race/ethnicity: White ~86.5%, Black ~8.5%, Other ~5.0%; - SES: Parental education – some college or higher, 53.3%; Household income ≥$50,000, 35.6%; - Anthropometry: BMI, Mean~17.5; Blood lipids at baseline, Mean:; - TC (mmol/L): ~5.17; - LDL (mmol/L): ~3.38; - HDL (mmol/L): ~1.48; - Triglycerides (mmol/L): ~0.90; - No statistically significant differences between intervention and control groups at baseline; Summary of findings:; In children with elevated LDL cholesterol, counseling to adhere to a diet providing less than 8% energy from SFA, up to 9% energy from PUFA, and less than 75mg/kcal of cholesterol, compared to usual care, reduced total, LDL, and HDL cholesterol or triglycerides after 5y and ~7y of follow-up. | Interventions/Comparators:; - [underlined: Intervention] (n=283): Counseling to adhere to a diet providing less than 8% energy from SFA, up to 9% energy from PUFA, less than 75mg/1000kcal of cholesterol, and 28% energy from total fat.; - [underlined: Control] (n=265): Usual care; [underlined: Intervention duration]: ~7 years (Intervention group: 6 weekly and 5 biweekly sessions during 1^st^ 6mo; 6 sessions during 2^nd^ 6mo; 4-6 sessions during 2^nd^ and 3^rd^ years; 4 sessions annually from 4^th^ year on); [underlined: Intervention compliance]: Fat intake measured at Final (Median: 7.2y, range: 6.5-9.3y) follow-up via multiple 24hr recalls, Mean for intervention vs control:; - SFA (%E): 10.2 vs 11.3, p<0.001; - Cholesterol (mg/1000kcal): 99 vs 103, p>0.05; Outcomes and assessment methods:; - Assessed at baseline (~9.5y of age), 1y*, 3y*, 5y, and Final (Median: 7.2y, range: 6.5-9.3y) follow-ups; - [underlined: Blood lipids:] TC, LDL, HDL, triglycerides (NR if fasting or non-fasting); *1y and 3y blood lipid results reported in Kwiterovich, 1995 | Blood lipids at 5y, 7.2y of follow-up; [underlined: TC,] mmol/L, Mean (SD); Intervention: 4.54 (0.58), 4.64 (0.62); Control (ref): 4.60 (0.67), 4.66 (0.68); Group differences, Mean (95% CI):; 5y F/U: −0.07 (−0.16, 0.03), p=0.18; 7.2y F/U: −0.03 (−0.13, 0.07), p=0.59; [underlined: LDL,] mmol/L, Mean; Intervention: 2.84, 2.95; Control (ref): 2.90, 3.00; Group differences, Mean:; 5y F/U: Data NR in mmol/L, p=0.11; 7.2y F/U: Data NR in mmol/L, p=0.25; [underlined: HDL,] mmol/L, Mean (SD); Intervention: 1.31 (0.29), 1.29 (0.29); Control (ref): 1.32 (0.26), 1.27 (0.25); Group differences, Mean (95% CI):; 5y F/U: −0.02 (−0.06, 0.02), p=0.28; 7.2y F/U: 0.01 (−0.03, 0.04), p=0.62; [underlined: Triglycerides,] mmol/L, Mean (SD); Intervention: 1.13 (0.66), 1.13 (0.58); Control (ref): 1.07 (0.53), 1.10 (0.50); Group differences, Mean (95% CI):; 5y F/U: 0.07 (−0.02, 0.17), p=0.12; 7.2y F/U: 0.04 (−0.05, 0.12), p=0.30 | Model adjustments:; Sex, baseline value of outcome variable, age at final visit (for final visit only); Limitations:; - Although dietary fats was the focus of the intervention, increased dietary fiber with an emphasis on fruits, vegetables, and whole grains was also encouraged; - No preregistered statistical analysis plan for 5y and Final follow-up analyses; Funding sources:; NHLBI
Dorgan, 2011 (https://www.ncbi.nlm.nih.gov/pubmed/21994964) ^6^; RCT, DISC, U.S.; Baseline N=301 Analytic N=214 (Attrition: 29%); Participant characteristics at baseline:; - Female children with LDL cholesterol values at the 80^th^ – 98^th^ percentile for age and sex at study entry; - Age: Mean=9.2y; - Sex (female): 100%; - Race/ethnicity: White ~90%, Black ~6%, Other 4%; - SES: NR; - Anthropometry: BMI z-score, Mean=0.2; Blood lipids and BP at baseline:; - NR; Summary of findings:; In female children with elevated LDL cholesterol, counseling to adhere to a diet providing less than 8% energy from SFA, up to 9% energy from PUFA, and less than 75mg/kcal of cholesterol, compared to usual care, did not affect LDL and HDL cholesterol, or triglyceride levels at ~27y of age after 16-20y of follow-up. The intervention group had lower SBP at ~27y of age compared to the control group, but no difference in DBP. | Interventions/Comparators:; - [underlined: Intervention] (n=108): Counseling to adhere to a diet providing less than 8% energy from SFA, up to 9% energy from PUFA, less than 75mg/1000kcal of cholesterol, and 28% energy from total fat.; - [underlined: Control] (ref, n=106): Usual care; [underlined: Intervention duration]: ~7 years (Intervention group: 6 weekly and 5 biweekly sessions during 1^st^ 6mo; 6 sessions during 2^nd^ 6mo; 4-6 sessions during 2^nd^ and 3^rd^ years; 4 sessions annually from 4^th^ year on); [underlined: Intervention compliance]: Fat intake measured at 16-20y follow-up via 3, non-consecutive 24hr recalls, Median (IQR) for intervention vs control:; - SFA (%E): 9.8 (7.9-12.0) vs 11.3 (9.5-13.3), p<0.001; - MUFA (%E): 11.1 (9.0-13.0) vs 11.8 (10.2-13.6), p=0.07; - PUFA (%E): 6.6 (5.4-8.2) vs 6.2 (5.4-7.3), p=0.18; Outcomes and assessment methods:; - Assessed at 16-20y follow-up (~27y of age); - [underlined: BP:] SBP, DBP; Measured in triplicate; - [underlined: Fasting blood lipids:] LDL, HDL, triglycerides | Blood levels at 16-20y of follow-up; [underlined: LDL,] mg/dL, Mean (SD); Intervention: 119.9 (27.8); Control (ref): 118.1 (24.3); P=0.62; [underlined: HDL,] mg/dL, Mean (95% CI); Intervention: 59.5 (57.0, 62.0); Control (ref): 59.6 (57.1, 62.2); P=0.94; [underlined: HDL <50 mg/dL,] %; Intervention: 24.4%; Control (ref): 24.8%; P=0.99; [underlined: Triglycerides,] mg/dL, Mean (95% CI); Intervention: 82.6 (76.2. 89.4); Control (ref): 82.4 (76.0, 89.4); P=0.98; [underlined: Triglycerides ≥150 mg/dL,] %; Intervention: 12.2%; Control (ref): 17.4%; P=0.35; [underlined: SBP,] mmHg, Mean (95% CI); Intervention: 107.7 (105.8, 109.6); Control (ref): 110.3 (108.3, 112.2); P=0.02; [underlined: DBP,] mmHg, Mean (95% CI); Intervention: 67.6 (65.8, 69.4); Control (ref): 68.2 (66.4, 70.0); P=0.59; [underlined: BP ≥130/≥85 mmHg or using BP medication,] %; Intervention: 3.4%; Control (ref): 7.1%; P=0.25; *Note: No significant differences between groups detected in unadjusted analyses. | Model adjustments:; Age at randomization, baseline BMI, baseline value of metabolic syndrome component, age at visit, race, education, hormone use, number of full-term pregnancies, leisure physical activity during past year, alcohol ingestion, cigarette smoking, current BMI, current intake of energy, SFA, PUFA, MUFA, cholesterol, insoluble and soluble fiber; carbohydrates (HDL and triglycerides only); sodium, calcium, potassium, magnesium (BP only); Limitations:; - Although dietary fats was the focus of the intervention, increased dietary fiber with an emphasis on fruits, vegetables, and whole grains was also encouraged; - No preregistered statistical analysis plan for 16-20y follow-up; Funding sources:; NCI
FiSK (Fish, children, health and cognition) Junior
Vuholm, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/31595295) ^36^; RCT, FiSK Junior, Denmark; Baseline N=199 Analytic N=197 (Attrition: 1%); Participant characteristics at baseline:; - Age: Median~9.6y; - Sex (female): ~49%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI, Mean~16.4; Blood lipids and BP at baseline, Mean:; - TC (mmol/L): ~4.15; - LDL (mmol/L): ~2.24; - HDL (mmol/L): ~1.54; - Triglycerides (mmol/L): Median~0.50; - SBP (mmHg): ~101; - DBP (mmHg): ~62; Summary of findings:; Children randomized to consume food rich in LCPUFAs (oily fish) for 12 weeks, compared to children randomized to consume food low in LCPUFAs (poultry), had higher total cholesterol, higher HDL cholesterol, and lower triglycerides. LDL cholesterol, SBP, and DBP were not affected by the intervention. | Interventions/Comparators:; - [underlined: Oily fish] (n=99): ~300g/wk (1.4-4.1g n-3 LCPUFA/100g); served 2x/wk for dinner and ≥3x/wk for lunch; - [underlined: Poultry] (ref; n=98): ~300g/wk (0.0-0.3g n-3 LCPUFA/100g); served 2x/wk for dinner and ≥3x/wk for lunch; [underlined: Intervention duration]: 12 weeks; [underlined: Intervention compliance]: Assessed with precoded, daily recording sheets and FFQs (baseline and endpoint) completed by parents; - Oily fish and poultry consumption increased in their respective groups; - Oily fish group EPA+DHA intake: Baseline, 135 (141) mg/d; Endpoint, 913 (278) mg/d; Outcomes and assessment methods:; - Assessed at baseline and endpoint (12 wk); - [underlined: Fasting blood lipids:] TC, LDL, HDL, triglycerides; - [underlined: BP:] SBP and DBP; Measured in triplicate | Between-group differences at endpoint, adjusted for baseline values; [underlined: TC,] mmol/L, Mean difference (95% CI); Poultry (ref) vs Oily fish: 0.15 (0.03, 0.28), P=0.02; [underlined: LDL,] mmol/L, Mean difference (95% CI); Poultry (ref) vs Oily fish: 0.08 (−0.02, 0.17), P=0.10; [underlined: HDL,] mmol/L, Mean difference (95% CI); Poultry (ref) vs Oily fish: 0.07 (0.01, 0.13), P=0.02; [underlined: Triglycerides,] mmol/L, Mean difference (95% CI); Poultry (ref) vs Oily fish: −0.05 (−0.11, −0.00), P=0.04; [underlined: SBP,] mmHg, Mean difference (95% CI); Poultry (ref) vs Oily fish: −0.7 (−2.0, 0.6), P=0.29; [underlined: DBP,] mmHg, Mean difference (95% CI); Poultry (ref) vs Oily fish: −0.1 (−1.1, 0.9) P=0.79; Results were similar when stratified by sex except for triglycerides, where an effect of group was detected in boys but not girls. | Model adjustments:; Blood lipids: Baseline value; Blood pressure: Baseline value, Baseline height and device used; Limitations:; - Fish intake used as a proxy for LCPUFAs; Other types of fat (SFA, MUFA, cholesterol) not reported or considered; - No preregistered statistical analysis plan for 5y and Final follow-up analyses; Funding sources:; Nordea-fonden; Food provided at discount from Skagenfood A/S, Sodam A/S, REMA1000 Danmark A/S; Food provided in kind from Amanda Seafoods A/S
Special Turku Coronary Risk Factor Intervention Project (STRIP)
Lapinleimu, 1995 (https://pubmed.ncbi.nlm.nih.gov/7861873) ^14^; RCT, STRIP, Finland; Baseline N=1,062 Analytic N=807 (Attrition: 24% from 7mo to 13mo); Participant characteristics at [underlined: baseline (7mo)]:; - Age: ~7mo; - Sex (female): 51.3%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: Weight-for-height: ~4% higher than Finnish mean based on Finnish growth curve; No group differences in growth from 7mo to 13mo; Fat intake at [underlined: baseline (8mo)], Mean (subset of formula-fed infants):; - SFA: ~13%E; ~11.8 g/day; - MUFA: ~9%E; ~7.9 g/day; - PUFA: ~5%E; ~4.4 g/day; - Cholesterol: ~71.3 mg/day; - No group differences at baseline; Blood lipids at [underlined: baseline (7mo)], Mean:; - Total cholesterol: ~3.98 mmol/L; - HDL cholesterol: ~0.89 mmol/L; - No group differences at baseline; Summary of findings:; Total cholesterol and HDL cholesterol decreased significantly more in the intervention group than in the control group between 7 months and 13 months. | Intervention/Control:; - [underlined: Intervention] (n=403): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day at 7, 8, 10 and 13 months; - [underlined: Control] (n=404): Basic health education of current PUFA/SFA ratio of 0.3-0.4 at 7 and 13 months; [underlined: Intervention duration:] 6 months; [underlined: Intervention compliance:] Assessed via 3-day food diary completed by family, assessed at 8 and 13 months; Fat intake at [underlined: follow-up (13mo)], Mean (SD), Intervention vs control:; - SFA: 9%E (3) vs 13%E (3), P<0.001; 9.3 (3.5) g/day vs 14.5 (4.8) g/day, P<0.001; - MUFA: 10%E (3) vs 9%E (2), P=0.02; 10.4 (3.2) g/day vs 10.1 (3.3) g/day, P=0.66; - PUFA: 5%E (2) vs 4%E (1), P<0.001; 5.8 (2.2) g/day vs 4.4 (1.4) g/day, P<0.001; - Cholesterol (mg/d): 83.8 (36.6) vs 112.8 (44.2), P<0.001; Outcomes and assessment methods:; - Assessed at 7mo (baseline) and 13mo; - [underlined: Non-fasting blood lipids:] TC, HDL | [underlined: TC], mmol/L, Mean (SD), Intervention vs Control; Blood lipid levels at 13mo; 3.96 (0.70) vs 4.22 (0.78), P=NR; Change from 7mo to 13mo; −0.03 (0.72) vs 0.24 (0.64), P<0.001; [underlined: HDL], mmol/L, Mean (SD), Intervention vs Control; Blood lipid levels at 13mo; 0.87 (0.19) vs 0.91 (0.19), P=NR; Change from 7mo to 13mo; −0.04 (0.19) vs 0.01 (0.17), P<0.001 | Model adjustments:; None; Limitations:; - Although intervention primarily focused on types of fats, dietary advice included importance of physical activity and avoidance of passive smoking; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Mannerheim League for Child Welfare, the Finnish Cardiac Research Foundation, the Medical Council of the Academy of Finland, the Yrjo Jahnsson Foundation, the Foundation for Paediatric Research, Finland, Piltti Foundation, the Juho Vainio Foundation, the Turku University Foundation, and Van den Bergh Foods Company
Routi, 1996 (https://www.ncbi.nlm.nih.gov/pubmed/8602597) ^30^; RCT, STRIP, Finland; Baseline N=1,062 Analytic N=784 (Attrition from 7mo to 24mo: 26%); Participant characteristics at [underlined: follow-up (24mo)]:; - Age: ~24mo; - Sex (female): NR; - Race/ethnicity: NR; - SES: NR; - Anthropometry: NR; Fat intake at [underlined: follow-up (24mo)], Mean (SD), Intervention vs Control:; - SFA (%E): 10.8 (2.8) vs 14.3 (3.0), P<0.001; - MUFA (%E): 10.4 (2.3) vs 10.8 (2.0), P<0.01; - PUFA (%E): 5.3 (1.4) vs 4.5 (1.4), P<0.001; - LA (%E): 4.3 (1.2) vs 3.6 (1.3), P<0.001; - LA (%FA): 14.5 (3.7) vs 11.0 (3.4), P<0.001; Summary of findings:; Total cholesterol was significantly lower in the intervention group than in the control group at 2 years. HDL cholesterol was significantly lower in the intervention group than in the control group at 2 years. | Intervention/Control:; - [underlined: Intervention] (n=394): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day at 7, 8, 10, 13, 15, 18, 21 mo and 2y; - [underlined: Control] (n=390): Basic health education of current PUFA/SFA ratio of 0.43 for children aged 1-2y at 7, 13 months, and 2 years; [underlined: Intervention duration:] ~1.5 years; [underlined: Intervention compliance:] Assessed via 3-day (8 and 13 months) or 4-day (2y) food diaries completed by family, assessed at 8mo, 13mo, and 2y; Outcomes and assessment methods:; - Assessed at 7mo (baseline), 13mo, and 2y; - [underlined: Non-fasting blood lipids:] TC, HDL | [underlined: TC], mmol/L, Mean (SD), Intervention vs Control; Blood lipid levels at 2y; 4.08 (0.69) vs 4.32 (0.77), P<0.001; [underlined: HDL], mmol/L, Mean (SD), Intervention vs Control; Blood lipid levels at 2y; 0.97 (019) vs 1.02 (0.19), P<0.001 | Model adjustments:; None; Limitations:; - Although intervention primarily focused on types of fats, dietary advice included importance of physical activity and avoidance of passive smoking; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Turku University Foundation, the Cardiac Research Foundation, Finland, The Yrjo Jahnsson Foundation, the Varsinais-Suomi Fund of the Finnish Cultural Foundation, The Arvo ja Inkeri Suominen Fund, the Lydia Maria Julin Fund, the Medical Council of the Finnish Academy, the Juho Vainio Foundation, the Foundation for Pediatric Research, Finland, the Mannerheim League for the Wellfare of Children, Chymos Ltd, and Van den Bergh Foods, Finland
Simell, 2000 (https://pubmed.ncbi.nlm.nih.gov/11063474) ^31^; RCT, STRIP, Finland; Baseline N=1,062 Analytic N=843 (Attrition from 7mo to 3y: 30%); Participant characteristics at [underlined: follow-up (3y)]:; - Age: ~3y; - Sex (female): 48%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: Growth from 7mo-3y: NS between groups; Fat intake at [underlined: follow-up (3y),] Mean (SD), Intervention vs Control:; - PUFA:SFA: 0.48 (0.17) vs 0.33 (0.13), P<0.0001, 95% CI: 0.12, 0.17; - Unsaturated FA:SFA: 1.38 (0.37) vs 1.08 (0.24), P<0.0001, 95% CI: 0.25, 0.34; - Cholesterol (mg/1000 kJ): 28 (10) vs 33 (11), P<0.0001, 95% CI: −6, −3; Summary of findings:; Total cholesterol was significantly lower by 3-6% in the intervention group than in the control group between 7 months and 3 years. This was significant only for males when stratified by sex. HDL cholesterol was significantly lower by 3-6% in the intervention group than in the control group from 7 months to 3 years. | Intervention/Control:; - [underlined: Intervention] (n=374; Boys, n=201; Girls, n=173): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day at 7, 8, 10, 13, 15, 18, 21 months, 2y to 3y, twice/year; - [underlined: Control] (n=374; Boys, n=187; Girls, n=187): Basic health education of current PUFA/SFA ratio of 0.3-0.4 at 7, 13, 18 months, 2y, and 3y; [underlined: Intervention duration:] ~2.5y; [underlined: Intervention compliance:] Assessed via 3-day food diary (8, 13, and 18mo) or 4-day food diary (≥2y) completed by family, assessed at 8, 13, 18mo, and biannually ≥2y; Outcomes and assessment methods:; - Assessed at 7mo, 13mo, 2y, and 3y; - [underlined: Non-fasting blood lipids:] TC, HDL | [underlined: TC], mmol/L, Mean (SD), Intervention vs Control; Blood lipid levels at 3y; Boys: 4.12 (0.63) vs 4.44 (0.79), P=NR; Girls: 4.45 (0.80) vs 4.49 (0.69), P=NR; Mean difference from 13mo-3y, adjusted for 7mo; All; TC was lower in intervention than control children between 7mo and 36mo, Data=NR, 95% CI: −0.27, −0.12, P<0.0001; Boys: 0.32 (0.76) vs 0.57 (0.65); 95% CI: −0.39, −0.20, P<0.0001; Girls: 0.23 (0.82) vs 0.37 (0.76); 95% CI: −0.21, 0.01, P=0.09; [underlined: HDL], mmol/L, Mean (SD), Intervention vs Control; Blood lipid levels at 3y; Boys: 1.05 (0.23) vs 1.12 (0.22), P=NR; Girls: 1.05 (0.20) vs 1.08 (0.21), P=NR; Mean difference from 13mo-3y, adjusted for 7mo; All; HDL was lower in intervention than in control children between 7mo and 3y, Data=NR, 95% CI: −0.07, −0.03, P<0.0001; Boys: 0.15 (0.23) vs 0.21 (0.19); 95% CI: −0.08, −0.03, P=0.0001; Girls: 0.15 (0.20) vs 0.18 (0.20); 95% CI: −0.07, −0.01, P=0.007 | Model adjustments:; Baseline value (7mo); Limitations:; - Although intervention primarily focused on types of fats, dietary advice included importance of physical activity, avoidance of passive smoking, and salt intake.; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Mannerheim League for Child Welfare, the Finnish Cardiac Research Foundation, the Foundation for Paediatric Research, Finland, Piltti Foundation, the Juho Vainio Foundation, the Turku University Foundation, and Van den Bergh Foods Company
Rask-Nissila, 2000 (https://pubmed.ncbi.nlm.nih.gov/11004136/) ^29^; RCT, STRIP, Finland; Baseline N=1,062 Analytic N=683 (Attrition from 7mo to 5y: 36%); Participant characteristics at [underlined: follow-up (5y)]:; - Age: ~5y; - Sex (female): 49%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: Height-for-age, weight-for-height, and BMI at 5y did not vary by group; Fat intake at follow-up (5y), Mean (SD), Intervention vs Control:; - SFA (%E): Boys: 11.9 (2.2) vs 14.5 (2.5), P=0.0001; Girls: 11.7 (2.5) vs 14.3 (2.7), P=0.0001; - MUFA (%E): Boys, 10.7 (1.9) vs 11.2 (2.0), P=0.06; Girls, 10.7 (2.0) vs 11.0 (1.8), P=0.036; - PUFA (%E): Boys, 5.2 (1.2) vs 4.9 (1.2), P=0.02; Girls, 5.2 (1.1) vs 4.8 (1.2), P=0.001; - Cholesterol (mg): Boys, 168.2 (63.5) vs 193.0 (71.0), P=0.002; Girls, 163.9 (60.2) vs 188.1 (72.2), P=0.004; Summary of findings:; Total cholesterol was significantly lower in intervention boys than in control boys between 7 months and 5 years; this was not significant among girls. HDL cholesterol was significantly lower in the intervention group than in the control group between 7 months and 5 years. LDL cholesterol was significantly lower in intervention boys than in control boys at 5 years; this was not significant among girls. Triglycerides were not significantly different between groups. | Intervention/Control:; - [underlined: Intervention] (n=339; Boys, n=181; Girls, n=158): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day at 7mo, 8mo, 10mo, 13mo, 15mo, 18mo, 21mo, 2y, 2.5y, 3y, 4y, and 5y; - [underlined: Control] (n=344; Boys, n=170, Girls, n=174): Basic health education of current PUFA/SFA ratio of 0.3-0.4 at 7mo, 13mo, 24mo, 3y, 4y, and 5y; [underlined: Intervention duration:] ~4.5 y; [underlined: Intervention compliance:] Assessed via 3-day (<2y) or 4-day (≥2y) food diary completed by family ~biannually; Outcomes and assessment methods:; - Assessed at 7mo, 13mo, 2y, 3y, 4y, and 5y; - [underlined: Blood lipids:] TC, HDL (Non-fasting <5y; fasting at 5y); LDL, triglycerides (only fasting at 5y) | [underlined: TC], mmol/L, Mean (SD),; [underlined: Boys (Intervention vs Control):]; 4y: 4.09 (0.60) vs 4.40 (0.70); 5y: 4.14 (0.62) vs 4.41 (0.72); Change, 7mo-5y: 0.35 (0.77) vs 0.57 (0.65); Mean difference (95% CI), 13mo to 5y:; −0.39 (−0.52, −0.26), P<0.0001; Equality of slopes (13mo-5y): P=0.06; [underlined: Girls (Intervention vs Control):]; 4y: 4.42 (0.65) vs 4.41 (0.79); 5y: 4.47 (0.72) vs 4.53 (0.74); Change, 7mo-5y: 0.32 (0.80) vs 0.35 (0.73); Mean difference (95% CI), 13mo to 5y:; −0.146 (−0.293, −0.0001), P=0.052; Equality of slopes (13mo-5y): P=0.19; [underlined: HDL], mmol/L, Mean (SD); [underlined: Boys (Intervention vs Control):]; 4y: 1.11 (0.22) vs 1.16 (0.22); 5y: 1.19 (0.25) vs 1.22 (0.25); Change, 7mo-5y: 0.29 (0.23) vs 0.32 (0.22); Mean difference (95% CI), 13mo to 5y:; −0.07 (−0.11, −0.03), P=0.0007; Equality of slopes (13mo-5y): P=0.27; [underlined: Girls (Intervention vs Control):]; 4y: 1.14 (0.18) vs 1.12 (0.22),; 5y: 1.18 (0.21) vs 1.19 (0.23); Change, 7mo-5y: 0.29 (0.23) vs 0.28 (0.22); Mean difference (95% CI), 13mo to 5y:; −0.05 (−0.09, −0.01), P=0.007; Equality of slopes (13mo-5y): Between-group differences decreased over time, P=0.023; [underlined: LDL], mmol/L, Mean (SD); [underlined: Boys (5y):] 2.62 (0.55) vs 2.87 (0.61); Difference at 5y: 95% CI: −0.39, −0.12, P=0.0002; [underlined: Girls (5y):] 2.94 (0.63) vs 2.99 (0.66); Difference at 5y: 95% CI: −0.21, 0.11, P=0.53; [underlined: Triglycerides], mmol/L, Mean (SD), Intervention vs Control; [underlined: Boys (5y):] 0.66 (0.23) vs 0.63 (0.21); Difference at 5y: P=0.25; [underlined: Girls (5y):] 0.69 (0.21) vs 0.69 (0.24); Difference at 5y: P=0.90 | Model adjustments:; Baseline (7mo) blood lipids; Limitations:; - Although intervention primarily focused on types of fats, dietary advice included importance of physical activity, avoidance of passive smoking, and salt intake; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Mannerheim League for Child Welfare; Finnish Cardiac Research Foundation; Foundation for Paediatric Research, Finland; Academy of Finland; Yrjo Jahnsson Foundation; Sigrid Juselius Foundation; Juho Vainio Foundation; Turku University Foundation; Finnish Cultural Foundation; Varsinais-Suomi Fund; City of Turku; Raisio Group; Van den Bergh Foods Company
Kaitosaari, 2003 (https://pubmed.ncbi.nlm.nih.gov/12885748/) ^10^; RCT, STRIP, Finland; Baseline N=1,062 Analytic N=640 (Attrition from 7mo to 7y: 40%); Participant characteristics at [underlined: follow-up (7y)]:; - Age: ~7y; - Sex (female): 45.3%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: NR; Fat intake at [underlined: follow-up (7y)], Mean (SD, Intervention vs Control:; - SFA, Boys: 16.2g (4.9) vs 20.5g (5.5), P<0.0001; - SFA, Girls: 15.6g (4.6) vs 19.4g (5.0), P<0.0001; - PUFA:SFA, Boys: 0.48 (0.16) vs 0.34 (0.15), P<0.0001; - PUFA:SFA, Girls: 0.48 (0.17) vs 0.34 (0.11), P<0.0001; - Cholesterol, Boys: 118 mg/1000 kcal (40) vs 137 mg/1000 kcal (50), P=0.0002; - Cholesterol, Girls: 123 mg/1000 kcal (45) vs 137 mg/1000 kcal (44), P=0.008; Summary of findings:; Total cholesterol levels were lower in intervention children than control children at 7 years. When stratified by sex, intervention boys had significant decreases in total cholesterol between 7 months and 13 months, 48 months, and 7 years. Intervention girls had significant decreases in HDL cholesterol between 7 months and 13 months, but not between 7 months and 48 months and 7 years. LDL cholesterol and triglycerides were significantly lower in intervention boys than control boys. This was not significant among girls. | Intervention/Control:; - [underlined: Intervention] (n=315; Boys, n=134; Girls, n=112): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day at 7, 8, 10, 13, 15, 18, 21 months; from 2y to 7y, counseling twice/year; - [underlined: Control] (n=325; Boys, n=140; Girls, n=125): Basic health education of current PUFA/SFA ratio of 0.3-0.4 at 7, 13 months, 2y to 7y twice a year; [underlined: Intervention duration:] ~6.5 years; [underlined: Intervention compliance:] Assessed via 3-day food diary (8, 13, and 18mo) or 4-day food diary (≥2y) completed by family/child, assessed biannually; Outcomes and assessment methods:; - Assessed at 7mo, 13mo, 3y, 5y, 7y mo; - [underlined: Blood lipids:] TC, HDL, LDL, Triglycerides (Nonfasting at 7mo, 13mo and 3y; Fasting at ≥5y) | [underlined: TC], mmol/L, Mean (SD), Intervention vs Control; [underlined: Male]; 13mo: 3.68 (0.61) vs 4.18 (0.70); 7y: 4.20 (0.64) vs 4.41 (0.66), P=0.003, 95% CI: −0.348, −0.071; [underlined: Female]; 13mo: 4.19 (0.73) vs 4.31 (0.78); 7y: 4.55 (0.66) vs 4.57 (0.72), P=0.78, 95% CI: −0.181, 0.135; Change from 7mo to 7y:; [underlined: Male:] 0.42 (0.70) vs 0.55 (0.63); [underlined: Female:] 0.40 (0.87) vs 0.43 (0.78); Difference in change from 7mo to:; [underlined: Male:] (Group*Time: P≤0.05); 13mo: −0.394, 95% CI: −0.508, −0.280; 4y: −0.298, 95% CI: −0.401, −0.196; 7y: −0.200, 95% CI: −0.331, −0.069; Mean difference from 13mo to 7y; [underlined: Female]: (Group*Time: P>0.05); −0.090, 95% CI: −0.213, 0.032, P=0.15; [underlined: HDL], mmol/L, Mean (SD), Intervention vs Control; [underlined: Male]; 13mo: 0.86 (0.19) vs 0.92 (0.20); 7y: 1.29 (0.24) vs 1.29 (0.25), P=1.00, 95% CI: −0.053, 0.053; [underlined: Female]; 13mo: 0.85 (0.19) vs 0.89 (0.17); 7y: 1.28 (0.20) vs 1.27 (0.22), P=0.82, 95% CI: −0.042, 0.052; Change from 7mo to 7y; Male: 0.37 (0.21) vs 0.38 (0.21); Female: 0.39 (0.21) vs 0.38 (0.21); Difference in change from 7mo to:; [underlined: Female:] (Group*Time: P≤0.05); 13mo: −0.049, 95% CI: −0.082, −0.016; 4y: −0.017, 95% CI:−0.047, 0.013; 7y: 0.016, 95% CI: −0.030, 0.062; Mean difference from 13mo to 7y; [underlined: Male]: −0.054, 95% CI: −0.086, −0.022, P=0.001; Group*Time: P>0.05; [underlined: LDL], mmol/L, Mean (SD), Intervention vs Control; [underlined: Male] (Interv: n=170; Cont: n=170); 2.63 (0.55) vs 2.82 (0.58), P=0.002, 95% CI: −0.312, −0.071; [underlined: Female] (Interv: n=145; Cont: n=155); 2.94 (0.60) vs 2.98 (0.65), P=0.59 95% CI: −0.181, 0.104; Mean difference from 5y and 7y; [underlined: Male:]; LDL was lower in intervention than control boys between 5y and 7y. Difference: 95% CI: −0.333, −0.150, P<0.0001; [underlined: Female:] Data NR, P=0.18; [underlined: Triglycerides], mmol/L, Mean (SD), Intervention vs Control; [underlined: Male] Interv: n=170; Cont: n=170); 0.64 (0.26) vs 0.68 (0.30), P=0.30; [underlined: Female] (Interv: n=145; Cont: n=155); 0.71 (0.28) vs 0.68 (0.25), P=0.48; Mean difference from 5y to 7y; [underlined: Male]: Triglyceride tended to decrease in intervention boys and increase in control boys, P=0.042; [underlined: Female]: Data NR, P=0.75 | Model adjustments:; Analyses of “Mean difference from 13mo to 7y”: adjusted for 7mo (baseline) values; Limitations:; - Although intervention primarily focused on types of fats, dietary advice included importance of physical activity, avoidance of passive smoking, and salt intake.; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Juho Vainio Foundation, the Yrjo Jahnsson Foundation, the Finnish Cardiac Research Foundation, the Foundation for Paediatric Research, Finland, the Academy of Finland, the Sigrid Juselius Foundation, the Turku University Foundation, the Finnish Cultural Foundation, City of Turku, EVO funds of Turku University Central Hospital, and the Raisio Group Research Foundation
Kaitosaari, 2006 (https://pubmed.ncbi.nlm.nih.gov/16567815) ^11^; RCT, STRIP, Finland; Baseline N=200 Analytic N=167 (Attrition: 17%); Subsample of children available for detailed laboratory measurements; Participant characteristics at [underlined: follow-up (9y)]:; - Age: ~9y; - Sex (female): 51%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: Weight-for-height (deviation from mean of healthy Finnish children): Boys: ~1.2%, Girls: ~4.6%, NS between groups; Fat intake at [underlined: follow-up (9y)], Mean (SD), Intervention vs Control; - SFA (%E), Group difference: P<0.001; ○ Boys: 11.2 (1.9) vs 12.8 (2.1); ○ Girls: 11.2 (2.8) vs 14.2 (2.3); - MUFA (%E), Group difference: P=NS; ○ Boys: 11.59 (1.79) vs 10.83 (1.75); ○ Girls: 10.39 (1.62) vs 11.06 (1.95); - PUFA (%E), Group difference: P=0.0003; ○ Boys: 6.03 (1.12) vs 5.39 (1.20); ○ Girls: 5.49 (1.19) vs 4.80 (1.02); Summary of findings:; Triglycerides were significantly lower in intervention children than control children at 9 years. Total cholesterol, HDL, and LDL were not different between groups. | Intervention/Control:; - [underlined: Intervention] (n=78; Boys, n=35; Girls, n=43): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day at 7, 8, 10, 13, 15, 18, 21 months; from 2y to 9y, counseling twice/year; dietary information were given directly to child beginning at 7y; - [underlined: Control] (n=89; Boys, n=47; Girls, n=42): Basic health education of current PUFA/SFA ratio of 0.3-0.4 at 7mo, 13mo, 2y, 3y, 4y, and 5y; from 7mo to 7y twice/year; from 7y and older once/year; [underlined: Intervention duration:] ~8.5 years; [underlined: Intervention compliance:] Assessed via 3-day food diary (7mo to <2y) or 4-day food diary (≥2y) completed by family/child, assessed biannually; Outcomes and assessment methods:; - Assessed at 9y; - [underlined: Fasting blood lipids:] TC, HDL, LDL, Triglycerides | Blood lipid levels at 9y, Mean (SD), Intervention vs Control; [underlined: TC], mmol/L, Mean (SD); Male: 4.30 (0.66) vs 4.49 (0.85), P>0.05; Female: 4.55 (0.65) vs 4.64 (0.65), Group difference: P>0.05; [underlined: HDL], mmol/L, Mean (SD); Male: 1.33 (0.25) vs 1.37 (0.28), P>0.05; Female: 1.24 (0.20) vs 1.30 (0.24), Group difference: P>0.05; [underlined: LDL], mmol/L, Mean (SD); Male: 2.71 (0.48) vs 2.78 (0.76), P>0.05; Female: 2.95 (0.61) vs 2.97 (0.56), Group difference: P>0.05; [underlined: Triglycerides], mmol/L, Mean (SD); Male: 0.57 (0.21) vs 0.75 (0.38); Female: 0.79 (0.36) vs 0.83 (0.29); Group difference: P=0.018 | Model adjustments:; None; Limitations:; - Although intervention primarily focused on types of fats, dietary advice included importance of physical activity, avoidance of passive smoking, and salt intake.; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Juho Vainio Foundation, the Yrjo Jahnsson Foundation, the Finnish Cardiac Research Foundation, the Foundation for Paediatric Research, Finland, the Academy of Finland, the Sigrid Juselius Foundation, the Turku University Foundation, the Finnish Cultural Foundation, City of Turku, EVO funds of Turku University Central Hospital, and the Raisio Group Research Foundation
Raitakari, 2005 (https://pubmed.ncbi.nlm.nih.gov/16330680) ^28^; RCT, STRIP, Finland; Baseline N=453 Analytic N=369 (Attrition: 19%); Subset of children with ultrasound data at 11y (time-restricted cohort); Participant characteristics at [underlined: follow-up (11y)]:; - Age: ~11y; - Sex (female): 50.7%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI: ~18; Fat intake at [underlined: follow-up (11y)], Mean (SD), Intervention vs Control:; - SFA (%E), Boys: 10.8 (2.1) vs 13.2 (2.9), P<0.0001; - SFA (%E), Girls: 11.5 (2.9) vs 12.8 (2.7), P=0.001; - PUFA:SFA, Boys: 0.59 (0.19) vs 0.42 (0.14), P<0.0001; - PUFA:SFA, Girls: 0.53 (0.19) vs 0.41 (0.13), P<0.0001; Summary of findings:; In this sub-study, total cholesterol and LDL were significantly lower in intervention boys than control boys at 11 years. These effects were not statistically significant in girls. There was no significant effect of the intervention on blood pressure, HDL cholesterol, and triglycerides at 11 years. | Intervention/Control:; - [underlined: Intervention] (n=179; Boys, n=90; Girls, n=89): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day at 7, 8, 10, 13, 15, 18, 21, 24, 30, 36, 48, and 60 months; biannually from 2y to 20y; - [underlined: Control] (n=190, Boys, n=92; Girls, n=98): Basic health education of current PUFA/SFA ratio of 0.3-0.4 at 7, 13, 24, 36, 48, and 60 months; biannually from 7mo to 2y and annually from 2y to 20y; [underlined: Intervention duration:] ~10.5 years; [underlined: Intervention compliance:] Assessed via 4-day food diaries completed by family/child, assessed biannually; Outcomes and assessment methods:; - Assessed at 11y; - [underlined: BP]: SBP and DBP; Measured in triplicate; - [underlined: Fasting blood lipids:] TC, HDL, LDL, Triglycerides | Blood lipid levels and BP at 11y; [underlined: TC], mmol/L, Mean (SD), Intervention vs Control; Boys: 4.37 (0.57) vs 4.58 (0.85), P=0.03; Girls: 4.53 (0.72) vs 4.58 (0.80), P=0.62; [underlined: LDL], mmol/L, Mean (SD), Intervention vs Control; Boys: 2.64 (0.52) vs 2.92 (0.75), P=0.009; Girls: 2.84 (0.62) vs 2.87 (0.72), P=0.70; [underlined: HDL], mmol/L, Mean (SD), Intervention vs Control; Boys: 1.34 (0.28) vs 1.32 (0.28), P=0.86; Girls: 1.27 (0.23) vs 1.29 (0.26), P=0.41; [underlined: Triglycerides], mmol/L, Mean (SD), Intervention vs Control; Boys:0.82 (0.49) vs 0.78 (0.33), P=0.53; Girls: 0.91 (0.47) vs 0.87 (0.38), P=0.59; [underlined: SBP], mmHg, Mean (SD), Intervention vs Control; Boys: 105 (9) vs 104 (8), P=0.31; Girls: 103 (8) vs 105 (8), P=0.35; [underlined: DBP], mmHg, Mean (SD), Intervention vs Control; Boys: 63 (6) vs 63 (5), P=0.93; Girls: 63 (6) vs 63 (5), P=0.89 | Model adjustments:; None; Limitations:; - Although intervention primarily focused on types of fats, dietary advice was given on physical activity, avoidance of passive smoking, and salt intake; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Academy of Finland; City of Turku; Finnish Foundation for Pediatric Research; Finnish Foundation of Cardiovascular Research; Finnish Cultural Foundation; Government grants for Turku University Hospital; Juho Vainio Foundation; Mannerheim League for Child Welfare; Raisio Group Research Foundation; Social Insurance Institution of Finland; Turku University Foundation; Van den Bergh Foods Company; Yrjo Jahnsson Foundation; Sigrid Juselius Foundation
Niinikoski, 2007 (https://pubmed.ncbi.nlm.nih.gov/17698729) ^22^; RCT, STRIP, Finland; Baseline N=1062 Analytic N=532 (Attrition from 7mo to 14y: 50%); Participant characteristics at [underlined: follow-up (14y)]:; - Age: ~14y; - Sex (female): 49%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI did not differ by study group between 7mo and 14y (P=0.28); Fat intake at [underlined: follow-up (14y)]: Mean (SD), Intervention vs Control; - SFA (%E), P<0.001; ○ Boys: 12 (3) vs 13 (3); ○ Girls: 12 (3) vs 13 (3); Summary of findings:; Total cholesterol, LDL cholesterol, and triglycerides in intervention boys were significantly higher between 7 months and 14 years than control boys. LDL cholesterol was significantly lower in intervention girls than control girls. HDL cholesterol did not differ between groups. | Intervention/Control:; - [underlined: Intervention] (n=254; Boys, n=135; Girls, n=119): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day at 7, 8, 10, 13, 15, 18, 21 months, 2y to 14y, counseling twice/year; dietary information were given directly to child beginning at 7y; - [underlined: Control] (n=278; Boys, n=141; Girls, n=137): Basic health education of current PUFA/SFA ratio of 0.3-0.4 at 7mo to 7y twice/year; from 7y to 14y once/year; [underlined: Intervention duration:] ~13.5y; [underlined: Intervention compliance:] Assessed via 3-day (<2y) or 4-day (≥2y) food diaries completed by family, assessed ~annually from 7mo to 14y; Outcomes and assessment methods:; - Assessed at 7, 13, months and 2y to 14y annually; - [underlined: Blood lipids:] TC, HDL, LDL, Trig (Non-fasting from 7mo-4y; fasting at 5y to 14y) | Blood lipid levels at 14y, Mean (SD); [underlined: TC], mmol/L, Mean (SD), Intervention vs Control; Boys: 3.91 (0.59) vs 4.11 (0.77); Mean difference from 7mo to 14y: P<0.001; Girls: 4.23 (0.63) vs 4.30 (0.79); Mean difference from 7mo to 14y: P=0.12; [underlined: HDL], Intervention vs Control; Boys: Data NR; Mean difference from 7mo to 14y: P>0.05; Girls: Data NR; Mean difference from 7mo to 14y: P>0.05; [underlined: LDL], Intervention vs Control; Boys: Data NR,; Mean difference from 5y to 14y: P<0.05; Girls: Data NR; Mean difference from 5y to 14y: P<0.05; [underlined: Triglycerides], Intervention vs Control; Boys: Data NR; Mean difference from 5y to 14y: P<0.001; Girls: Data NR; Mean difference from 5y to 14y: P>0.05 | Model adjustments:; Energy intake, SFA (%E) intake, height, and BMI; Limitations:; - Although intervention primarily focused on types of fats, dietary advice was given on physical activity, avoidance of passive smoking, and salt intake; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Finnish Cardiac Research Foundation, Foundation for Pediatric Research, Finland, Academy of Finland, Yrjo Jahnsson Foundation, Sigrid Juselius Foundation, Special Federal Research Funds for Turku University Hospital, Turku University Foundation, Turku University Hospital Foundation, Juho Vainio Foundation, Finnish Cultural Foundation
Niinikoski, 2009 (https://pubmed.ncbi.nlm.nih.gov/19364991) ^21^; RCT, STRIP, Finland; Baseline N=1062 Analytic N=524 (Attrition from 7mo to 15y: 51%); Participant characteristics at [underlined: follow-up (15y)]:; - Age: ~15y; - Sex (female): 48%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: NR; Fat intake at [underlined: follow-up (15y)], Mean (SD), Intervention vs Control; - SFA (%E): 11.1 (2.4) vs 12.8 (3.0), P<0.001*; - MUFA (%E): 10.9 (2.4) vs 10.6 (2.1), P=0.12*; - PUFA (%E): 5.9 (1.6) vs 5.4 (.6), P<0.001*; *Based on repeated measures ANOVA between 8mo and 15y; BP at [underlined: baseline (7mo)]: NR; Summary of findings:; Diastolic and systolic blood pressure was significantly lower in intervention children than control children. When stratified by gender, girls and boys in the intervention group had significantly lower diastolic BP, but not systolic BP, than those in the control group. | Intervention/Control:; - [underlined: Intervention] (n=248; Boys, n=133; Girls n=115): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day at 7, 8, 10, 13, 15, 18, 21 months, 2y to 15y biannually; - [underlined: Control] (n=276; Boys, n=139; Girls, n=137): Basic health education of current PUFA/SFA ratio of 0.3-0.4 at 7mo to 15y; biannually from 7mo to 7y and annually from 7y to 15y; [underlined: Intervention duration:] ~14.5 years; [underlined: Intervention compliance:] Assessed via 3-day (<2y) or 4-day (≥2y) food diaries completed by family/child, assessed biannually; Outcomes and assessment methods:; - Assessed annually from 7mo to 15y; - [underlined: BP:] measured 1x per visit from 7mo to 7y, 2-4x per visit from 8-9y, 2x per visit after 9y; Mean values for each visit were used in statistical analyses | [underlined: SBP], mmHg, Mean (SD), Intervention vs Control; Blood pressure values at 15y; Girls: 113.6 (10.2) vs 114.8 (11.9), P=0.38; Boys: 120.8 (13.2) vs 122.0 (12.3), P=0.42; Mean difference from 7mo to 15y; −1.0, 95% CI: −1.7, −0.2, P=0.018 (children in intervention group had lower systolic BP than children in control group); [underlined: DBP], mmHg, Mean (SD), Intervention vs Control; Blood pressure values at 15y; Girls: 60.2 (6.0) vs 61.9 (6.9), P=0.048; Boys: 60.8 (7.2) vs 62.7 (7.5), P=0.045; Mean difference from 7mo to 15y; −1.0, 95% CI: −1.5, −0.4, P<0.001 (children in intervention group had lower diastolic BP than children in control group) | Model adjustments:; None; Limitations:; - Although intervention primarily focused on types of fats, dietary advice included importance of physical activity, avoidance of passive smoking, and salt intake, and ample use of vegetables, fruits, berries and whole grain products, and increase fiber; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Finnish Cardiac Research Foundation, Foundation for Pediatric Research, Finland, Academy of Finland, Mannerheim League for Child Welfare, Yrjo Jahnsson Foundation, Sigrid Juselius Foundation, Federal Research Funds for Turku University Hospital, Turku University Foundation, Turku University Hospital Foundation, Juho Vainio Foundation, Finnish Cultural Foundation, city of Turku
Hakanen, 2010 (https://pubmed.ncbi.nlm.nih.gov/20002624) ^8^; RCT, STRIP, Finland; Baseline N=1062 Analytic N=525 (Attrition from 7mo to 15y: 51%); Participant characteristics at [underlined: follow-up (15y)]:; - Age: ~15y; - Sex (female): 48%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI: ~20.5, P=0.31 between groups; Fat intake at [underlined: follow-up (15y)]: NR; Summary of findings:; Diastolic blood pressure was significantly lower for intervention children than control children at 15 years. There were no significant effects of the intervention on HDL cholesterol, triglycerides, and systolic blood pressure at 15 years. | Intervention/Control:; - [underlined: Intervention] (n=249; Boys, n=133; Girls, n=116): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day at 7mo, 8mo, 10mo, 13mo, 15mo, 18mo, 21mo, 2y, 2.5y, 3y, 4y, and 5y; biannually from 2y to 15y; - [underlined: Control] (n=276; Boys, n=139; Girls, n=137): Basic health education of current PUFA/SFA ratio of 0.3-0.4 at 7, 13, 24, 36, 48, and 60 months; biannually from 7mo to 2y and annually from 2y to 15y; [underlined: Intervention duration:] ~14.5 years; [underlined: Intervention compliance:] Assessed via 4-day food diary completed by family/child, assessed biannually; Outcomes and assessment methods:; - Assessed at 15y; - [underlined: BP]: SBP and DBP; Measured in duplicate; - [underlined: Fasting blood lipids:] HDL, Triglycerides | Blood lipid levels and BP at 15y; [underlined: HDL], mmol/L, Mean (SD), Intervention vs Control; Boys: 1.08 (0.22) vs 1.08 (0.22); Girls: 1.23 (0.21) vs 1.21 (0.24); Group difference: P=0.43; [underlined: Triglycerides], mmol/L, Mean (SD), Intervention vs Control; Boys: 0.85 (0.49) vs 0.96 (0.48); Girls: 0.93 (0.41) vs 0.92 (0.54); Group difference: P=0.25; [underlined: SBP], mmHg, Mean (SD), Intervention vs Control; Boys: 121 (13) vs 122 (12); Girls: 114 (10) vs 115 (12); Group difference: P=0.25; [underlined: DBP], mmHg, Mean (SD), Intervention vs Control; Boys: 61 (7.1) vs 63 (7.5); Girls: 60 (6.0) vs 62 (6.9); Group difference: P=0.005 | Model adjustments:; None; Limitations:; - Although intervention primarily focused on types of fats, dietary advice included importance of physical activity, avoidance of passive smoking, and salt intake, and ample use of vegetables, fruits, berries and whole grain products, and increase fiber; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Academy of Finland, Finnish Cardiac Research Foundation, Finnish Cultural Foundation, Special Federal Research Funds for Turku University Hospital, Research Foundation of Orion Corporation, C.G. Sundell Foundation, Yrjo Jahnsson Foundation, Maud Kuistila Foundation, Juho Vainio Foundation, Finnish Medical Society Duodecim and Foundation for Pediatric Research
Niinikoski, 2012 (https://pubmed.ncbi.nlm.nih.gov/22331346) ^23^; RCT, STRIP, Finland; Baseline N=1062 Analytic N=442 (Attrition from 7mo to 19y: 58%); Participant characteristics at [underlined: follow-up (19y)]:; - Age: ~19y; - Sex (female): 49.8%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI: ~19.9; [underlined: SFA intake (%E)] at [underlined: follow-up (15y, 16y, 17y, 18y, 19y)], Mean (SD), Intervention vs Control; - 15y: Boys, 11.2 (2.3) vs 13.1 (2.9); Girls, 11.0 (2.5) vs 12.5 (3.2); - 16y: Boys, 11.8 (2.6) vs 13.4 (2.9); Girls, 11.2 (2.5) vs 12.5 (2.8); - 17y: Boys, 11.7 (2.6) vs 13.1 (3.0); Girls, 11.6 (3.0) vs 12.2 (2.9); - 18y: Boys, 11.2 (2.6) vs 12.8 (3.0); Girls, 11.6 (2.7) vs 11.9 (3.1); 19y: Boys, 11.8 (2.5) vs 12.7 (3.2); Girls, 11.4 (2.4) vs 12.0 (2.8); Summary of findings:; Intervention boys who received nutrition counseling intervention (1:1:1 ratio of PUFA:MUFA:SFA) from 7 months to 20 years, compared to control boys who received basic health education at 7 months to 20 years, had significant lower total cholesterol, LDL, and triglycerides at 20 years. These effects were not significant in girls at 20 years. There were no significant effect of the intervention on HDL for both genders at 20 years. | Intervention/Control:; - [underlined: Intervention] (n=201): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day at 7, 8, 10, 13, 15, 18, 21, 24, 30, 36, 48, and 60 months; biannually from 2y to 19y; - [underlined: Control] (ref; n=241): Basic health education of current PUFA/SFA ratio of 0.3-0.4 at 7, 13, 24, 36, 48, and 60 months; biannually from 7mo to 2y and annually from 2y to 19y; [underlined: Intervention duration:] ~18.5y; [underlined: Intervention compliance:] 3-day or 4-day food diaries completed by family/child, assessed biannually or annually from 7mo-19y; - SFA (%E), Group differences (95% CI) from 7mo-19y, Intervention vs Control (ref); - Boys: −2.1 (−2.3, −1.9), P<0.001; - Girls: −1.9 (−2.1, −1.7), P<0.001; Outcomes and assessment methods:; - Assessed ~annually from 7mo to 19y; - [underlined: Blood lipids:] TC, HDL, LDL, Triglycerides; Non-fasting 7mo-4y, Fasting from 5y-19y | [underlined: TC], mmol/L; Mean (SD), Intervention vs Control (ref); Boys:; 15y: 3.64 (0.59) vs 3.89 (0.78); 16y: 3.68 (0.57) vs 3.88 (0.75); 17y: 3.71 (0.55) vs 3.91 (0.72); 18y: 3.77 (0.57) vs 4.05 (0.78); 19y: 4.00 (0.69) vs 4.16 (0.82); Mean difference (95% CI) from 7mo-19y: −0.20 (−0.28, −0.13); Girls:; 15y: 4.11 (0.58) vs 4.22 (0.85); 16y: 4.22 (0.71) vs 4.17 (0.79); 17y: 4.41 (0.81) vs 4.31 (0.73); 18y: 4.49 (0.77) vs 4.43 (0.76); 19y: 4.57 (0.78) vs 4.56 (0.76); Mean difference (95% CI) from 7mo-19y: −0.07 (−0.15, 0.02); [underlined: HDL], mmol/L; Mean (SD), Intervention vs Control; Boys:; 15y: 1.08 (0.22) vs 1.08 (0.22); 16y: 1.05 (0.22) vs 1.05 (0.23); 17y: 1.07 (0.21) vs 1.06 (0.21); 18y: 1.11 (0.24) vs 1.13 (0.22); 19y: 1.20 (0.24) vs 1.14 (0.24); 95% CI of mean difference from 7mo-19y: −0.03, 0.02, P=0.81; Girls:; 15y: 1.23 (0.21) vs 1.21 (0.69); 16y: 1.26 (0.26) vs 1.22 (0.27); 17y: 1.35 (0.29) vs 1.31 (0.25); 18y: 1.42 (0.28) vs 1.38 (0.26); 19y: 1.48 (0.28) vs 1.44 (0.30); 95% CI of mean difference from 7mo-19y: −0.02, 0.03, P=0.75; [underlined: LDL*], mmol/L; Mean (SD), Intervention vs Control; Boys:; 15y: 2.18 (0.54) vs 2.38 (0.68); 16y: 2.23 (0.52) vs 2.37 (0.66); 17y: 2.22 (0.52) vs 2.39 (0.64); 18y: 2.25 (0.50) vs 2.46 (0.70); 19y: 2.33 (0.56) vs 2.52 (0.73); 95% CI of mean difference from 5y-19y: −0.26, −0.10, P<0.001; Girls:; 15y: 2.45 (0.53) vs 2.59 (0.71); 16y: 2.52 (0.58) vs 2.54 (0.68); 17y: 2.58 (0.66) vs 2.57 (0.63); 18y: 2.60 (0.64) vs 2.58 (0.68); 19y: 2.57 (0.67) vs 2.62 (0.68); 95% CI of mean difference from 5y-19y: −0.17, −0.01, P=0.037; *Additional analyses using alternative derivation of LDL reported with similar directionality and magnitude of group differences.; [underlined: Triglycerides], mmol/L; Mean (SD), Intervention vs Control; Boys:; 15y: 0.80 (0.48) vs 0.91 (0.48); 16y: 0.87 (0.44) vs 0.96 (0.42); 17y: 0.89 (0.39) vs 0.96 (0.49); 18y: 0.89 (0.35) vs 1.01 (0.48); 19y: 1.03 (0.74) vs 1.10 (0.46); Mean difference (95% CI) from 5y-19y: −0.06 (−0.10, −0.03), P=0.001; Girls:; 15y: 0.88 (0.40) vs 0.87 (0.53); 16y: 0.94 (0.40) vs 0.87 (0.38); 17y: 1.02 (0.46) vs 0.93 (0.39); 18y: 1.04 (0.48) vs 1.00 (0.41); 19y: 1.48 (0.28) vs 1.44 (0.30); 95% CI of mean difference from 5y-19y: −0.02, 0.03, P=0.75 | Model adjustments:; Age, age*study group if P<0.05; Limitations:; - Although intervention primarily focused on types of fats, dietary advice included importance of physical activity, avoidance of passive smoking, and salt intake, and ample use of vegetables, fruits, berries and whole grain products, and increase fiber; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Mannerheim League for Child Welfare; Finnish Cardiovascular Research Foundation; Foundation for Peadiatric Research, Finland; Academy of Finland; Public Health Challenge Research Programme; Juho Vainio Foundation; Yrjo Jahnsson Foundation; Sigrid Juselius Foundation; Turku University Foundation; Special Federal Research Funds for Turku University Hospital; Turku University Hospital Foundation; Finnish Cultural Foundation; Finnish Ministry of Education and Culture
Lehtovirta, 2018 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5864506/) ^15^; RCT, STRIP, Finland; Baseline N=554 Analytic N=417 (Attrition from 9y to 19y: 25%); Participant characteristics at [underlined: follow-up (19y)]:; - Age: ~19y; - Sex (female): 48%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI ~22; Fat intake at baseline (19y):; - SFA (%E): Boys: −2.0, 95% CI: −1.7, −2.3; Girls: −1.8, 95% CI: −1.5, −2.1, P<0.0001 (lower in intervention than control group for boys and girls); - MUFA (%E): NS between groups; - PUFA (%E): Boys: 0.5, 95% CI: 0.4, 0.6; Girls: 0.6, 95% CI: 0.5, 0.8, P<0.0001 (higher in intervention than control group for boys and girls); Summary of findings:; Total cholesterol and LDL cholesterol were significantly lower for all intervention children than control children between 9 years and 19 years. When stratified by gender, there were no significant effect of the intervention on total cholesterol. LDL cholesterol and triglycerides were significantly lower in intervention boys than control boys. This was not significant for girls. No significant effects were found in HDL. | Intervention/Control:; - [underlined: Intervention] (n=NR): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day between 7 months and 19 years; Biannually from 2-19y; - [underlined: Control] (n=NR): Basic health education of current PUFA/SFA ratio of 0.3-0.4 at 7, 13 months, biannually from 7mo-7y and annually from 7y-20y; [underlined: Intervention duration:] ~19.5y; [underlined: Intervention compliance:] Assessed via 4-day food diary completed by child, assessed biannually; Outcomes and assessment methods:; - Assessed at 9, 11, 13, 15, 17, 19y; - [underlined: BP]: NR; - [underlined: Fasting blood lipids:] TC, HDL, LDL, Trig | Differences in blood lipid between groups, Pooled analyses across 6 time points (9y n=554, 11y n=553, 13y n=508, 15y n=517, 17y n=457, 19y n=417); [underlined: TC], mmol/L, Pooled mean (SD); All: P=0.01; Boys: 3.64 (0.82), B: −0.114, P=0.07; Girls: 3.93 (0.87), B: −0.123, P=0.09; [underlined: HDL], mmol/L, Pooled mean (SD); All: P=0.75; Boys: 1.32 (0.29), B: 0.018, P=0.46; Girls: P=0.87; [underlined: LDL], mmol/L, Pooled mean (SD); All: P=0.007; Boys: 1.24 (0.42), B:−0.069, P=0.04; Girls: 1.37 (0.45), B: −0.071, P=0.08; [underlined: Triglycerides], mmol/L, Pooled mean (SD); All: NR; Boys: 0.77 (0.34), B: −0.086, P<0.001; Girls: 0.84 (0.35), B: 0.011, P=0.69; [underlined: SBP], mmHg, Mean (SD), Intervention vs Control; Boys: 126.9 (12.1) vs 129.0 (13.4), P=NR; Girls: 116.2 (10.2) vs 115.1 (12.6), P=NR; [underlined: DBP], mmHg, Mean (SD), Intervention vs Control; Boys: 65.9 (7.8) vs 66.3 (8.2), P=NR; Girls: 64.9 (6.3) vs 65.4 (7.7), P=NR | Model adjustments:; Age, sex; Limitations:; - Although intervention primarily focused on types of fats, dietary advice included importance of physical activity, avoidance of passive smoking, and salt intake, and ample use of vegetables, fruits, berries and whole grain products, and increase fiber; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Academy of Finland, Juho Vainio Foundation, Finnish Cultural Foundation, Finnish Foundation for Cardiovascular Research, Sigrid Juselius Foundation, Yrjo Jahnsson Foundation, Finnish Diabetes Research Foundation, Novo Nordisk Foundation, Strategic Research Funding from the University of Oulu, Finnish Ministry of Education and Culture, Special Governmental Grants for Health Sciences and Research, Turku University Hospital, University of Turku Foundation
Nupponen, 2015 (https://pubmed.ncbi.nlm.nih.gov/25605660) ^24^; RCT, STRIP, Finland; Baseline N=534 Analytic N=407 (Attrition from 15 to 20y: 24%); Participant characteristics at [underlined: follow-up (20y)]:; - Age: ~20y; - Sex (female): 50%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI ~22.8; Fat intake at follow-up (20y): NR; Summary of findings:; Children who received a nutrition counseling intervention (1:1:1 ratio of PUFA:MUFA:SFA) from 7 months to 20 years, compared to children who received basic health education at 7 months to 20 years, had a lower risk of high blood pressure at 20y, but no effect was seen on continuous SBP or DBP from 15-20y. Intervention boys had a lower risk of high triglycerides at 20y and lower triglyceride levels from 15-20y compared to control boys. There were no significant effect of the intervention on HDL or triglycerides (in girls). | Intervention/Control:; - [underlined: Intervention] (n=181): Nutrition counseling (20-45 minutes) aimed at a diet with 30-35% of energy from fat, proportions of PUFA, MUFA, SFA of 1:1:1, and cholesterol intake <200 mg/day at 7mo, 8mo, 10mo, 13mo, 15mo, 18mo, 21mo, 2y, 2.5y, 3y, 4y, and 5y months; biannually from 2y to 20y; - [underlined: Control] (ref; n=226): Basic health education of current PUFA/SFA ratio of 0.3-0.4 at 7mo, 13mo, 2y, 3y 4y, and 5y months; biannually from 7mo to 2y and annually from 2y to 20y; [underlined: Intervention duration:] ~19.5y; [underlined: Intervention compliance:] 3-day or 4-day food diary, assessed biannually or annually from 7mo-19y; Outcomes and assessment methods:; - Assessed annually from 15 to 20y; - [underlined: BP:] SBP and DBP; Measured in duplicate; - [underlined: Fasting blood lipids:] HDL, Triglycerides; - Cut-offs for dichotomous outcomes set using cohort-based percentiles | [underlined: HDL], mmol/L, Mean (SD), Intervention vs Control (ref); 20y: 1.35 (0.34) vs 1.33 (0.32); Group differences from 15-20y: P=0.17; [underlined: Low HDL], RR (95% CI), Intervention vs Control (ref); ≤20^th^ percentile: 0.96 (0.75, 1.23); ≤15^th^ percentile: 0.95 (0.71, 1.27); ≤10^th^ percentile: 0.80 (0.55, 1.16); [underlined: Triglycerides], mmol/L, Mean (SD), Intervention vs Control (ref); Girls:; 20y: 1.10 (0.70) vs 1.00 (0.70); Group differences from 15-20y: P=0.19; Boys:; 20y: 0.80 (0.60) vs 1.00 (0.60); Group differences from 15-20y: P=0.019; [underlined: High triglycerides], RR (95% CI), Intervention vs Control (ref); Girls:; ≥80^th^ percentile: 1.25 (0.95, 1.65); ≥85^th^ percentile: 1.25 (0.91, 1.71); ≥90^th^ percentile: 1.44 (0.97, 2.15); Boys:; ≥80^th^ percentile: 0.71 (0.54, 0.94); ≥85^th^ percentile: 0.62 (0.44, 0.86); ≥90^th^ percentile: 0.67 (0.44, 1.00); [underlined: SBP], mmHg, Mean (SD), Intervention vs Control (ref); 20y: 121.1 (11.8) vs 121.9 (14.8); Group differences from 15-20y: P=0.47; [underlined: DBP], mmHg, Mean (SD); 20y: 65.4 (7.6) vs 66.5 (8.3); Group differences from 15-20y: P=0.25; [underlined: High SBP and/or DBP], RR (95% CI), Intervention vs Control (ref); ≥80^th^ percentile: 0.83 (0.70, 0.99); ≥85^th^ percentile: 0.77 (0.62, 0.95); ≥90^th^ percentile: 0.79 (0.61, 1.02) | Model adjustments:; Sex by group interaction (triglycerides only); Limitations:; - Although intervention primarily focused on types of fats, dietary advice included importance of physical activity, avoidance of passive smoking, and salt intake, and ample use of vegetables, fruits, berries and whole grain products, and increase fiber; - Some concern for risk of bias in missing outcome data due to attrition; - Serious risk of bias in selection of the reported result due to multiple outcome measurements; Funding sources:; Academy of Finland; Finnish Ministry of Education and Culture; Finnish Cultural Foundation; Finnish Cardiac Research Foundation; Sigrid Juselius Foundation; Yrjo Jahnsson Foundation; Juho Vainio Foundation; Special Governmental Grants for Health Sciences Research, Turku University Hospital; Turku University Foundation
RCT: Crossover Design
Ballesteros, 2004 (https://www.ncbi.nlm.nih.gov/pubmed/15447890) ^2^; RCT crossover, Mexico; Baseline N=60 Analytic N=54 (Attrition: 10%); Participant characteristics at baseline:; - Age: Mean~10.4y; - Sex (female): 54%; - Race/ethnicity: NR; - SES: 100% from low SES area of Hermosillo, Mexico; - Anthropometry: BMI, Mean~19.6; Blood lipids and BP at baseline, Mean:; - TC (mmol/L): ~3.5; - LDL (mmol/L): ~1.7; - HDL (mmol/L): ~1.3; - Triglycerides (mmol/L): ~1.2; - SBP (mmHg): ~102; - DBP (mmHg): ~64; Summary of findings:; In children, consuming 2 whole eggs (providing 518mg cholesterol, 3g SFA, and 6g MUFA) per day for 30 days lowered DBP (all participants) and increased LDL and HDL cholesterol (only among “hyperresponders”) compared to a cholesterol and fat free egg white substitute. | Interventions/Comparators:; - [underlined: Egg]: Two whole eggs (110g) per day (518mg cholesterol, 3g SFA, 6g MUFA); - [underlined: Substitute]: 110 g egg white substitute per day (0mg cholesterol, 0g SFA, 0g MUFA); - All subjects categorized as hyperresponders (increase TC ≥ 0.33 mmol/L) or hyporesponder (increase TC<0.29 mmol/L) in response to the Egg intervention; [underlined: Intervention duration]: 30 days (~4 weeks); [underlined: Intervention compliance]: Egg and substitute served at breakfast in school on weekdays; Parents monitored and interviewed to confirm consumption of egg and substitute on weekends; 98% compliance; Outcomes and assessment methods:; - Assessed at baseline/end of wash out period, after 30d of intervention; - [underlined: Fasting blood lipids:] TC, LDL, HDL, triglycerides; Measured in duplicate; - [underlined: BP:] SBP and DBP | Blood lipids and BP post-intervention; [underlined: LDL,] mmol/L, Mean (SD); Hyperresponders, Hyporesponders; Egg: 1.93 (0.36), 1.88 (0.42); Substitute (ref): 1.54 (0.38), 1.83 (0.44); Egg vs Substitute (ref): P<0.0001; Responder: P<0.001; Interaction: P<0.01; [underlined: HDL,] mmol/L, Mean (SD); Hyperresponders, Hyporesponders; Egg: 1.35 (0.29), 1.28 (0.19); Substitute (ref): 1.23 (0.26), 1.22 (0.19); Egg vs Substitute (ref): P<0.001; Responder: P<0.001; Interaction: P<0.05; [underlined: Triglycerides,] mmol/L, Mean (SD); Egg vs Substitute: p>0.05; [underlined: SBP,] mmHg, Mean (SD); Egg vs Substitute: p>0.05; [underlined: DBP,] mmHg, Mean (SD); Hyperresponders, Hyporesponders; Egg: 62.3 (3.2), 63.4 (4.5); Substitute (ref): 64.7 (4.0), 64.7 (5.2); Egg vs Substitute (ref): P<0.05 | Model adjustments:; None; Limitations:; - No information randomization process; - No preregistered statistical analysis plan and analyses without stratification by responder status NR; Funding sources:; American Egg Board; University of Connecticut Research Foundation
Denke, 2000 (https://www.ncbi.nlm.nih.gov/pubmed/11105179) ^5^; RCT crossover, U.S.; Baseline N=56 families, Analytic N=46 families (134 children), (Attrition: 18%); Participant characteristics at baseline:; - Age: Mean=12y, SD=4; - Sex (female): 47%; - Race/ethnicity: ~85% White, ~7% African American, ~4% Hispanic, ~2% Native American, ~2% Asian; - SES: NR; - Anthropometry: BMI, Mean=19.3, SD=4.3; Blood lipids at baseline, Mean (SD):; - TC (mg/dL): 152 (25); - LDL (mg/dL): 95 (22); - HDL (mg/dL): 46 (11); - Triglycerides (mg/dL): 74 (41); Summary of findings:; In children approximately 12 years of age, providing 25% energy from margarine compared to butter daily for 5 weeks significantly reduced total and LDL cholesterol and had no effect on HDL and triglyceride levels. | Interventions/Comparators:; - [underlined: Butter (ref)]: 25% energy from butter provided as spread or in specially formulated bakery product; - [underlined: Margarine]: 25% energy from margarine provided as spread or in specially formulated bakery products; - Expected intake: 21%E from test fat; [underlined: Intervention duration]: 5 weeks (Washout: >1mo, 3mo during November-January holidays); [underlined: Intervention compliance]: 3-d diet record during third and fourth weeks of intervention by family; inventories of unconsumed products by study personnel; daily check sheets by family members; - 3d diet record: Butter (18%E) vs Margarine period (21%E), P<0.01; - Inventory: Butter (83% of product) vs Margarine (88% of product), P=NR; Outcomes and assessment methods:; - Assessed at baseline and twice during last 2 weeks of each diet period.; - [underlined: Fasting blood lipids:] TC, LDL, HDL, triglycerides | Blood lipids post-intervention; [underlined: TC,] mg/dl, Mean (SD); Butter (ref): 161 (32); Margarine: 150 (25); Group differences, Mean (95% CI); −11.3 (−15.4, −7.2), P<0.001; [underlined: LDL], mg/dl, Mean (SD); Butter (ref): 104 (30); Margarine: 93 (23); Group differences, Mean (95% CI); −11.2 (−14.6, −7.7), P<0.001; [underlined: HDL], mg/dL, Mean (SD); Butter vs Margarine: P=0.80; [underlined: Triglycerides], mg/dL, Mean (SD); Butter vs Margarine: P=0.45 | Model adjustments:; Family membership, age, BMI, ad libitum LDL level, ApoE genotype, change in serum fatty acid CE levels; Limitations:; - The allocation sequence was not random and was not concealed; - No information provided on missing data; - No preregistered statistical analysis plan; Funding sources:; United Soybean Board; National Association of Margarine Manufacturers; University of Texas Southwestern GCRC grant.
Estevez-Gonzalez, 1998 (https://www.ncbi.nlm.nih.gov/pubmed/9470006) ^7^; RCT Crossover, Spain; Baseline N=88 Analytic N=88 (Attrition: 0%); Participant characteristics at baseline:; - Children 3-9y of age without family history of heart disease, metabolic disease, or hyperlipidemia; - Age: 3-9y; - Sex (female): 45.5%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI z-score, Mean=0.2; Blood lipids at baseline:; - NR; Summary of findings:; In children 3-9y of age, intake of a milk preparation with higher proportions of MUFAs and PUFAs, and lower proportions of SFAs and cholesterol than whole milk for 7mo, reduced total and LDL cholesterol and triglycerides compared to intake of whole milk for 7mo. | Interventions/Comparators:; - [underlined: Control]: ~500mL whole milk/d; 67% SFA, 30% MUFA, 3% PUFA; Cholesterol 107 mg/L; - [underlined: Intervention]: ~500mL milk preparation/d; 15% SFA, 70% MUFA, 15% PUFA; Cholesterol 22 mg/L; - Total fat in whole milk and milk preparation was equal; [underlined: Intervention duration]: 7 months; [underlined: Intervention compliance]: NR; Outcomes and assessment methods:; - Assessed at end of each 7mo-period; - [underlined: Fasting blood lipids:] TC, LDL, HDL, triglycerides | [underlined: TC,] mmol/L, Mean (SD); Control: 4.53 (0.90); Intervention: 4.2 (0.67); p<0.001; Children with elevated TC had a greater reduction in TC with the intervention compared to children with normal TC.; [underlined: LDL,] mmol/L, Mean (SD); Control: 2.73 (0.73); Intervention: 2.47 (0.55); p<0.001; Children with elevated TC had a greater reduction in LDL with the intervention compared to children with normal TC.; [underlined: HDL,] mmol/L, Mean (SD); Control: 1.41 (0.33); Intervention: 1.39 (0.28); p=NS; [underlined: Triglycerides,] mmol/L, Mean (SD); Control: 0.83 (0.39); Intervention: 0.72 (0.24); p<0.01 | Model adjustments:; None; Limitations:; - No information on whether the allocation sequence was random; - No preregistered statistical analysis plan; Funding sources:; NR
RCT: Cluster Design
Muros, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/25409189) ^18^; RCT Cluster, Spain; Baseline N=162 Analytic N=135 (Attrition: 17%); Participant characteristics at baseline:; - Age: Mean=10.7y, SD=0.5; - Sex (female): 49.6%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI, Mean=19.7, SD=3.7; Blood lipids and BP at baseline, Mean (SD):; - TC (mg/dL): 156.7 (24.8); - LDL (mg/dL): 86.9 (20.1); - HDL (mg/dL): 56.0 (12.8); - Triglycerides (mg/dL): 79.1 (25.7); - SBP and DBP: NR; Summary of findings:; Blood lipids and blood pressure did not differ between children who replaced their typical cooking oil with EVOO for 1mo while participating in a 6mo physical activity and nutritional education intervention and children who just participated in the physical activity and nutritional education intervention. | Interventions/Comparators:; - [underlined: PA+NE+EVOO] (n=20): Physical activity and nutritional education intervention with replacement of oil normally consumed with extra-virgin olive oil (EVOO); - [underlined: PA+NE] (n=25): Physical activity and nutritional education intervention; - Other groups NA to review: control (n=41), physical activity alone (n=28), nutritional education alone (n=21); [underlined: Intervention duration]: 6 months (1 month of EVOO); [underlined: Intervention compliance]: Compliance to EVOO NR; Compliance to PA and NE assessed via attendance at sessions, <75% attendance excluded.; Outcomes and assessment methods:; - Assessed at baseline (~10.7y) and 6mo follow-up; - [underlined: Fasting blood lipids:] TC, LDL, HDL, triglycerides; - [underlined: BP:] SBP and DBP; Measured in triplicate | Change in blood lipids or BP pre- to postintervention:; PA+NE vs PA+NE+EVOO; [underlined: TC,] mg/dL, Mean (SD); P>0.05; [underlined: LDL,] mg/dL, Mean (SD); P>0.05; [underlined: HDL,] mg/dL, Mean (SD); P>0.05; [underlined: Triglycerides,] mg/dL, Mean (SD); P>0.05; [underlined: SBP,] mmHg, Mean (SD); P>0.05; [underlined: DBP,] mmHg, Mean (SD); P>0.05; BP at post-intervention: PA+NE vs PA+NE+EVOO; [underlined: DBP,] mmHg, Mean difference (95% CI); P>0.05 | Model adjustments:; Baseline blood lipid level or blood pressure; Limitations:; - No information on randomization process; - No information on timing of subject identification and recruitment relative to timing of randomization; - No preregistered statistical analysis plan; Funding sources:; Mapfre Foundation; Direccion General de Investigacion and Gestion del Plan Ncional I+D+I; Consejeria de Innovacion de la Junta de Andalucia

* Abbreviations: BP – blood pressure, CI – confidence interval, DBP – diastolic blood pressure, F/U – follow-up, HDL – HDL cholesterol, kcal – kilocalorie(s), LDL – LDL cholesterol, NR – not reported, %E – percent energy, RCT – randomized controlled trial, ref – reference group, SBP – systolic blood pressure, SD – standard deviation, SES – socioeconomic status, TC – total cholesterol

† Statistically significant results bolded.

Table 2 Evidence from prospective cohort studies examining types of dietary fat consumed during childhood and cardiovascular disease intermediate and endpoint outcomes^*^

Study and Population Characteristics | Exposures, Comparators, Outcomes | Results^†^ | Key Confounders, Study Limitations
Cowin, 2001 (https://www.ncbi.nlm.nih.gov/pubmed/11303493) ^4^; PCS, ALSPAC, U.K.; Baseline N=1183, Analytic N=389 (Attrition: 67%); Participant characteristics at baseline:; - Age: ~18mo; - Sex (female): ~45%; - Race/ethnicity: 100% Caucasian; - SES: NR; - Anthropometry: NR; Fat intake at baseline: NR; Blood lipids baseline: NR; Summary of findings:; Associations between type and source of fat intake at 18mo and blood lipid levels at 31mo differed between boys and girls. Among boys, higher SFA intake was associated with higher TC, mean intake of PUFA was higher in those in the lowest quintile of TC compared to those in the highest quintile of TC, any consumption of butter was associated with higher TC, and weighed intake of non-polyunsaturated margarine was positively associated with TC. Among girls, higher PUFA intake was associated with higher HDL and weighed non-polyunsaturated margarine intake was associated with higher HDL. All other tested associations were not statistically significant. | Exposures:; - SFA (continuous; units NR); - PUFA (continuous; units NR); - MUFA (continuous; units NR); - PUFA:SFA ratio (continuous; units NR); - Cholesterol (continuous; units NR); - Butter (continuous and categorical [yes/no]; units NR); - Non-polyunsaturated margarine (continuous and categorical [yes/no]; units NR); - Polyunsaturated margarine (continuous and categorical [yes/no]; units NR); [underlined: Assessment method and timing]:; - 3-day unweighted diet record followed by an interview with trained study personnel; - Assessed at baseline (18mo); Outcomes and assessment methods:; - Assessed at 31mo; - [underlined: Non-fasting blood lipids:] TC, LDL, HDL | [underlined: TC], Beta (SE); [underlined: Boys (n=210)] \|; SFA: 0.0334 (0.010), P=0.001; MUFA, PUFA, Cholesterol: P>0.05; [underlined: Girls (n=175)]; SFA, MUFA, PUFA, Cholesterol: P>0.05; [underlined: HDL], Beta (SE); [underlined: Boys (n=NR)]; SFA, MUFA, PUFA, Cholesterol: P>0.05; [underlined: Girls (n=133)]; SFA: 0.0076 (0.004), P=0.080; PUFA: 0.113 (0.056), P=0.045; MUFA, Cholesterol: P>0.05; FA intake between lowest 20% (ref) vs highest 20% [underlined: TC] levels; [underlined: SFA], g, Means, Difference (95% CI); Boys: 21.1 vs 23.9, 2.8 (1.2, 4.5), P=0.001; Girls: P>0.05; [underlined: MUFA], g, Means, Difference (95% CI); Boys: P>0.05; Girls: P>0.05; [underlined: PUFA], g, Geometric means; Boys: 5.66 vs 4.77, P=0.01; Girls: P>0.05; [underlined: Cholesterol], mg, Geometric means; Boys: P>0.05; Girls: P>0.05; Correlation between blood lipids and FA intake (energy adjusted); [underlined: TC,] Correlation coefficient; [underlined: Boys (n=214)]: PUFA:SFA ratio: 0.174, P=0.011; [underlined: Girls (n=175)]: PUFA:SFA ratio: P>0.05; [underlined: LDL,] Correlation coefficient; [underlined: Boys (n=137)]; SFA: 0.174, P=0.042; PUFA:SFA ratio: 0.172, P=0.045; MUFA, PUFA, Cholesterol: P>0.05; [underlined: Girls (n=109)]; All: P>0.05; Blood lipids by food consumption (yes vs no); [underlined: HDL,] Correlation coefficient; [underlined: Boys (n=164):] PUFA:SFA ratio: P>0.05; [underlined: Girls (n=133)]: PUFA:SFA ratio: P>0.05; [underlined: TC], mmol/L, Mean (SD); [underlined: Girls and Boys:]; Butter, non-polyunsaturated margarine, polyunsaturated margarine: P>0.05; [underlined: HDL], mmol/L, Mean (SD); [underlined: Boys:]; Butter: Yes (n=34), 0.91 (0.26) vs No (n=130), 0.83 (0.19), P=0.047; Non-polyunsaturated margarine, polyunsaturated margarine: P>0.05; [underlined: Girls:]; Butter, non-polyunsaturated margarine, polyunsaturated margarine: P>0.05; Correlations between blood lipids and foods consumption (weight); [underlined: TC], Correlation coefficient; [underlined: Boys]; Non-polyunsaturated margarine: 0.219, P=0.047; Butter, polyunsaturated margarine: P>0.05; [underlined: Girls]; Butter, polyunsaturated margarine, non-polyunsaturated margarine: P>0.05; [underlined: HDL], Correlation coefficient; [underlined: Boys]; Butter, polyunsaturated margarine, non-polyunsaturated margarine: P>0.05; [underlined: Girls]; Non-polyunsaturated margarine: 0.368, P=0.021; Butter, polyunsaturated margarine: P>0.05 | Key confounders [underlined: NOT] accounted for: SES, family history of CVD or diabetes, physical activity; Key confounders accounted for: Sex, age, TEI, race/ethnicity; Additional model adjustments: Energy and the energy-adjusted intakes of SFA, MUFA, PUFA, cholesterol, starch, sugar, and vitamin C (backward regression models only), height (backward regression models in boys only); Limitations:; - Did not account for all key confounders; - Three day unweighted diet record not validated and method to assess exposures were not all clearly described; - No preregistered statistical analysis plan and concern for selective reporting; Funding sources:; Northern and Yorkshire Regional Health Authority NHS Research and Development Programme on Cardiovascular Disease and Stroke.
Twisk, 1996 (https://www.ncbi.nlm.nih.gov/pubmed/8827160) ^34^; PCS, Amsterdam Growth and Health Study, Netherlands; Baseline N=307 Analytic N=181 (Attrition: 41%); Participant characteristics at baseline:; - Age: Mean=13.1y, SD=0.8; - Sex (female): 54%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: NR; Fat intake at baseline, Mean (SD):; - SFA: Males, 16.6 (2.7) % of energy; Females, 15.5 (2.2) % of energy; - PUFA: Males, 6.1 (2.0) % of energy; Females, 5.9 (2.5) % of energy; - Cholesterol: Males, 29.4 (7.5) mg/MJ; Females, 30.2 (6.7) mg/MJ; Blood lipids at baseline:; - NR; Summary of findings:; During adolescence and early adulthood, consumption of PUFA and a higher PUFA:SFA ratio was associated with lower total cholesterol whereas consumption of SFA and cholesterol was associated with higher total cholesterol. No type of fat was associated with HDL cholesterol. | Exposures:; - PUFA:SFA ratio (continuous); - SFA (continuous; % energy); - PUFA (continuous; % energy); - Cholesterol (continuous; mg/MJ); [underlined: Assessment method and timing]:; - Cross-check dietary history interview assessing usual food consumption during past month, administered by a dietitian; - Assessed at baseline (13y), 14y, 15y, 16y, 21y, and 27y of age; Outcomes and assessment methods:; - Assessed at baseline (13y), 14y, 15y, 16y, 21y, and 27y of age; - [underlined: Non-fasting blood lipids:] TC, HDL | PUFA:SFA ratio; [underlined: TC,] Beta (95% CI); −0.07 (−0.12, −0.03), p=0.001; [underlined: HDL,] Beta (95% CI); Data NR, p=NS; SFAs; [underlined: TC,] Beta (95% CI); 0.05 (0.00, 0.10), p=0.04; [underlined: HDL,] Beta (95% CI); Data NR, p=NS; PUFAs; [underlined: TC,] Beta (95% CI); −0.06 (−0.09, −0.02), p<0.01; [underlined: HDL,] Beta (95% CI); Data NR, p=NS; Cholesterol; [underlined: TC,] Beta (95% CI); 0.08 (0.03, 0.12), p=0.002; [underlined: HDL,] Beta (95% CI); Data NR, p=NS | Key confounders [underlined: NOT] accounted for: Race/ethnicity, SES, TEI, physical activity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, TEI.; Additional model adjustments: Time, body fatness, lean body mass, cardiopulmonary fitness; Limitations:; - Not all key confounders accounted for; - Dietary history interview was not validated; - 41% attrition without sufficient information on whether responders differed from nonresponders; - No preregistered statistical analysis plan; Funding sources:; Dutch Heart Foundation; Dutch Prevention Fund; Dutch Ministry of Well Being and Public Health; Dairy Foundation on Nutrition and Health
Post, 1997 (https://www.ncbi.nlm.nih.gov/pubmed/9192197) ^26^; PCS, Amsterdam Growth and Health Study, Netherlands; Baseline N=307 Analytic N=182 (Attrition: 41%); Participant characteristics at baseline:; - Age: ~13y; - Sex (female): 54%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: NR; Fat intake at baseline:; - NR; Blood lipids and BP at baseline:; - NR; Summary of findings:; During adolescence and early adulthood, consumption of SFA was associated with higher total and HDL cholesterol, and lower DBP, consumption of PUFA was associated with lower total cholesterol, and consumption of cholesterol was associated with higher total cholesterol. All other diet-outcome associations were non-significant. | Exposures:; - SFAs (continuous; % energy); - PUFAs (continuous; % energy); - Cholesterol (continuous; mg/MJ); [underlined: Assessment method and timing]:; - Cross-check dietary history interview assessing usual food consumption during past month, administered by a dietitian; - Assessed at baseline (13y), 14y, 15y, 16y, 21y, and 27y of age; Outcomes and assessment methods:; - Assessed at baseline (13y), 14y, 15y, 16y, 21y, and 27y of age; - [underlined: BP:] SBP, DBP; - [underlined: Non-fasting blood lipids:] TC, HDL | SFAs; [underlined: SBP,] Beta (95% CI)*; Data NR, p=NS; [underlined: DBP,] Beta (95% CI)*; −0.067 (−0.13, 0.00), p=0.049; [underlined: TC,] Beta (95% CI)**; 0.60 (0.00, 0.12), p=0.03; [underlined: HDL,] Beta (95% CI)**; 0.072 (0.02, 0.13), p=0.014; PUFAs; [underlined: SBP,] Beta (95% CI)*; Data NR, p=NS; [underlined: DBP,] Beta (95% CI)*; Data NR, p=NS; [underlined: TC,] Beta (95% CI)**; −0.049 (−0.10, 0.00), p=0.042; [underlined: HDL,] Beta (95% CI)**; Data NR, p=NS; Cholesterol; [underlined: SBP,] Beta (95% CI)*; Data NR, p=NS; [underlined: DBP,] Beta (95% CI)*; Data NR, p=NS; [underlined: TC,] Beta (95% CI)**; 0.061 (0.01, 0.12), p=0.033; [underlined: HDL,] Beta (95% CI)**; Data NR, p=NS; *Results from univariate analyses (multivariate analyses not conducted); **Results from multivariate analyses | Key confounders [underlined: NOT] accounted for: Race/ethnicity, SES, physical activity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, TEI.; Additional model adjustments: Time, animal protein intake, SFA, PUFA, and cholesterol intake (multivariate analyses only).; Limitations:; - Not all key confounders accounted for; - Dietary history interview was not validated; - 41% attrition without sufficient information on whether responders differed from nonresponders; - No preregistered statistical analysis plan; Funding sources:; NR
Ness, 2005 (https://www.ncbi.nlm.nih.gov/pubmed/15958357) ^19^; PCS, Boyd Orr, U.K.; Baseline N=4,999 Analytic N=4,028 (Attrition: 19%); Participant characteristics at baseline:; - Age: Mean=7.5y, SD=4.8 (IQR: 3.5-11.2); - Sex (female): 50.5%; - Race/ethnicity: NR; - SES: Father’s social class: I 1.5%, II 7.2%, III 19.6%, IV 23.0%, V 14.3%, Unemployed 26.2%, Unclassifiable 8.2%; Townsend score (sum of standardized scores for levels of car ownership, house ownership, overcrowding, unemployment; negative values indicate less deprivation): −1.6 (range: −2.8 to 0.9); - Anthropometry: NR; Fat intake at baseline:; - See “Exposures” in next column.; Blood lipids and BP at baseline:; - NR; Summary of findings:; Consumption of SFAs during childhood was not associated with CHD or stroke mortality after ~60y of follow-up. | Exposures:; - SFAs (quartiles), Mean (SD; range); - Q1 (ref): 19.6 g/d (3.2; 8.8-24.0); - Q2: 27.6 g/d (2.3; 24.0-31.4); - Q3: 35.5 g/d (2.6; 31.4-40.4); - Q4: 52.0 g/d (10.8; 40.6-108.9); [underlined: Assessment method and timing]:; - Per capita intake calculated from seven-day weighed household inventory divided by number of household members and taking into account meals missed by family members and meals consumed by visitors; - Assessed at baseline (1937-1939); Outcomes and assessment methods:; - Assessed during ~60y of follow-up; - [underlined: CHD mortality and Stroke mortality:] Determined from death certificate | SFAs; [underlined: CHD mortality,] Rate ratio (95% CI); Q1 (ref); Q2: 0.81 (0.54, 1.21); Q3: 0.68 (0.43, 1.08); Q4: 0.70 (0.39, 1.26); p-trend: 0.20; [underlined: Stroke mortality,] Rate ratio (95% CI); Q1 (ref); Q2: 1.37 (0.74, 2.51); Q3: 0.71 (0.32, 1.58); Q4: 1.31 (0.49, 3.47); p-trend: 0.90 | Key confounders [underlined: NOT] accounted for: Race/ethnicity, physical activity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (father’s social class, Townsend score), TEI.; Additional model adjustments: Childhood family food expenditure, district of residence as child, period of birth, season when studied as child.; Limitations:; - Did not account for all key confounders; - Start of exposure and follow-up did not coincide; - SFA measured indirectly using 7d weighed household inventory divided by total number of household members irrespective of age or sex; - 19% attrition without information on those lost to follow-up; - No preregistered statistical analysis plan; Funding sources:; World Cancer Research Fund, Medical Research Council, British Heart Foundation
Nicklas, 2002 (https://www.ncbi.nlm.nih.gov/pubmed/11985407) ^20^; PCS, CATCH, U.S.; Baseline N=3,218 Analytic N=1,182 (Attrition: 63%); Participant characteristics at baseline:; - Age: Mean~8.7y; - Sex (female): 52%; - Race/ethnicity: 71% White, 15% Hispanic-American, 10% African-American, 25 Asian, 2% other; - SES: NR; - Anthropometry: Weight, Mean~31.3 kg; Height, Mean~1.32 m; Fat intake at baseline, Mean:; - SFA (g): ~29g; - MUFA (g): ~27g; - PUFA (g): ~13g; - Cholesterol (mg): ~221mg; Blood lipids at baseline, Mean:; - TC (mmol/L): ~77; - HDL (mmol/L): ~23; Summary of findings:; Saturated fat and unsaturated fat intake was associated with increased serum TC in children 8 to 10 years of age. Dietary cholesterol intake was not significantly associated with serum TC. | Exposures:; - SFA (continuous; g); - MUFA (continuous; g); - PUFA (continuous; g); - Unsaturated FA (continuous; PUFA+MUFA; g); - Cholesterol (continuous; mg); [underlined: Diet assessment method and timing]:; - Validated, food record-assisted 24-hour recalls; - Assessed at baseline (~8.7y) and 2y follow-up (~11y); Outcomes and assessment methods:; - Assessed at baseline (~8.7y) and 2y follow-up (~11y); - [underlined: Non-fasting blood lipids:] TC, HDL; absolute value assessed at baseline (~8.7y) and follow-up (~11y) | Replacement of other types of fat with SFA; [underlined: TC,] mmol/L, Beta (SE); 0.004 (0.002), P<0.04; [underlined: HDL,] mmol/L, Beta (SE); Data NR, P>0.05; Replacement of other types of fat with MUFA; [underlined: TC,] mmol/L, Beta (SE); P>0.05; [underlined: HDL,] mmol/L, Beta (SE); Data NR, P>0.05; Replacement of other types of fat with PUFA; [underlined: TC,] mmol/L, Beta (SE); P>0.05; [underlined: HDL,] mmol/L, Beta (SE); Data NR, P>0.05; Replacement of other types of fat with Unsaturated FA; [underlined: TC,] mmol/L, Beta (SE); 0.004 (0.002), P<0.03; [underlined: HDL,] mmol/L, Beta (SE); Data NR, P>0.05; Cholesterol; [underlined: TC,] mmol/L, Beta (SE); Data NR, P>0.05; [underlined: HDL,] mmol/L, Beta (SE); Data NR, P>0.05 | Key confounders [underlined: NOT] accounted for: SES, physical activity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity, TEI.; Additional model adjustments: Height, weight, CATCH site, intervention group, semester, and school.; Limitations:; - Did not account for all key confounders; - 63% attrition with no information on whether non-responders differed from responders; - No preregistered statistical analysis plan; Funding sources:; NHLBI
Magnussen, 2011 (https://www.ncbi.nlm.nih.gov/pubmed/21199983) ^16^; PCS, Childhood Determinants of Adult Health Study, Australia; Baseline N=2,809 Analytic N (including 9y olds)=539 (Attrition: 81%); Analytic N (excluding 9y olds)=302; Participant characteristics at baseline:; - Age: Mean 11.9y, SD=2.5 (Note: Only 12y, 15y old children with dietary data); - Sex (female): 50%; - Race/ethnicity: NR; - SES: Parental educational level: 40% School only, 29% Trade/vocational certificate, 31% University; - Anthropometry: BMI, Mean~18.5; Fat intake at baseline:; - SFAs (%E): ~16%; Blood lipids at baseline:; - TC (mg/dL): Mean~174; - LDL (mg/dL): Mean~105; - HDL (mg/dL): Mean~56; - Triglycerides (mg/dL): Median~58; Summary of findings:; Change in saturated fat intake between approximately 12/15y and 32/35y of age was not associated with blood lipid risk categories from youth to adulthood. | Exposures:; - Change in SFA intake (continuous; age- and sex-specific z-score); [underlined: Diet assessment method and timing]:; - 24hr record of food consumption; completed at baseline (12y and 15y of age); - Sum of 3 FFQ questions related to fat intake (type of milk usually consumed, frequency of trimming fat from meat, and type of spread usually used on bread); completed at 20y follow-up; Outcomes and assessment methods:; - Assessed at baseline (12y, 15y of age) and 20y follow-up; - [underlined: Fasting blood lipids:] TC, LDL, HDL, triglycerides; - Categorized based on pediatric and adult high-risk cut points:; - True-positive (TP): high-risk levels in youth and adulthood; - False-positive (FP): high-risk levels in youth, normal-risk levels in adulthood; - False-negative (FN): normal-risk levels in youth, high-risk levels in adulthood; - True-negative (TN): normal-risk levels in youth and adulthood | Change in SFA intake z-score by blood lipid risk category; [underlined: TC]; No differences between any risk categories (TP, FP, FN, TN): All P>0.05; [underlined: LDL]; No differences between any risk categories (TP, FP, FN, TN): All P>0.05; [underlined: HDL]; No differences between any risk categories (TP, FP, FN, TN): All P>0.05; [underlined: Triglycerides]; No differences between any risk categories (TP, FP, FN, TN): All P>0.05 | Key confounders [underlined: NOT] accounted for: Race/ethnicity, SES, TEI, physical activity, family history of CVD or diabetes; Key confounders accounted for: Sex, age; Additional model adjustments: None; Limitations:; - Did not account for all key confounders; - SFA intake assessment method validity and reliability unknown; - Analysis unlikely to have removed risk of bias arising from missing data; - No preregistered statistical analysis plan; Funding sources:; Commonwealth Departments of Sport, Recreation and Tourism, and Health; the National Heart Foundation; Common-wealth Schools Commission; National Health and Medical Research Council; the Heart Foundation, the Tasmanian Com- munity Fund; Veolia Environmental Services; Sanitarium; ASICS; Target.
Simons-Morton, 1997 (https://www.ncbi.nlm.nih.gov/pubmed/9095079) ^32^; PCS, DISC, U.S.; Baseline N=663 Analytic N=583 (Attrition: 12%); Participant characteristics at baseline:; - Children with LDL cholesterol values at the 80^th^ – 98^th^ percentile for age and sex who participated in RCT to assess effect of changing FA intake on CVD risk; - Age: Mean=9.6y, SD=0.72; - Sex (female): 46%; - Race/ethnicity: White ~86.5%, Black ~8.5%, Other ~5.0%; - SES: NR; - Anthropometry: Height, Mean=136.4 cm, SD=6.9; Weight, Mean=32.9 kg, SD=6.8; Fat intake at baseline, Mean (SD):; - SFA: 24.9 g (8.6 g); 12.9%E (2.7%E); - MUFA: 24.9 g (8.3 g); 12.9%E (2.4%E); - PUFA: 11.4 g (4.0 g), 5.9%E (1.6% E); - Cholesterol: 201.8 mg (101.7 mg); BP at baseline, Mean:; - SBP (mmHg): ~97.4; - DBP (mmHg): ~61.9; - No statistically significant differences between intervention and control groups at baseline; Summary of findings:; In children with elevated LDL cholesterol participating in an RCT to assess the effect of changing FA intake on CVD risk, intake of SFA, MUFA, PUFA, and cholesterol intake were not associated with blood pressure except for a statistically significant relationship between higher MUFA intake and higher DBP. | Exposures:; - SFAs (continuous; g); - PUFAs (continuous; g); - MUFAs (continuous; g); - Cholesterol (continuous; mg); [underlined: Assessment method and timing:]; - Three, non-consecutive 24-hr recalls conducted by trained dietitians at each time point; - Assessed at baseline (~9.6y), 1y, and 3y follow-ups; Outcomes and assessment methods:; - Assessed at baseline (~9.6y), 1y, and 3y follow-ups; - [underlined: BP:] SBP, DBP; Measured in duplicate | SFAs; [underlined: SBP,] mmHg, Beta; 0.065, p>0.05; [underlined: DBP,] mmHg, Beta; −0.049, p>0.05; MUFAs; [underlined: SBP,] mmHg, Beta; 0.021, p>0.05; [underlined: DBP,] mmHg, Beta; 0.13, p<0.05; PUFAs; [underlined: SBP,] mmHg, Beta; 0.027, p>0.05; [underlined: DBP,] mmHg, Beta; 0.040, p>0.05; Cholesterol; [underlined: SBP,] mmHg, Beta; −0.0033, p>0.05; [underlined: DBP,] mmHg, Beta; −0.0025, p>0.05 | Key confounders [underlined: NOT] accounted for: Race/ethnicity, SES, physical activity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, TEI; Additional model adjustments: Height, weight, other macro- and micronutrients; Limitations:; - Not all key confounders accounted for; - Intervention group was not controlled for in analyses; - No preregistered statistical analysis plan; Funding sources:; NHLBI
van den Hooven, 2013 (https://www.ncbi.nlm.nih.gov/pubmed/24068791) ^35^; PCS, Generation R, Netherlands; Baseline N=5,088 Analytic N=2,812 (Attrition: 45%); Participant characteristics at baseline:; - Age: Mean=14mo, SD=2mo; - Sex (female): 51.9%; - Race/ethnicity: Dutch ethnic background, 68.8%; - SES: Maternal educational level, Primary education 4.4%, Secondary 35.1%, Higher education 57.3%; - Anthropometry: Maternal BMI, Median=22.5, 95% range:18.3, 34.6; Fat intake at baseline:; - See “Exposures” in next column.; Blood lipids and BP at baseline:; - NR; Summary of findings:; Consumption of SFAs, MUFAs, or PUFAs at ~14mo of age were not associated with blood pressure at 6y of age. | Exposures:; - SFAs (tertiles); - <13.3 g/d (ref); - 13.3-16.5 g/d; - >16.5 g/d; - MUFAs (tertiles); - <11.5 g/d (ref); - 11.5-14.6 g/d; - >14.6 g/d; - PUFAs (tertiles); - <7.0 g/d (ref); - 7.0-8.6 g/d; - >8.6 g/d; [underlined: Diet assessment method and timing]:; - Self-administered, validated 211-item FFQ completed by parents/caregivers; - Assessed at baseline (14 mo); Outcomes and assessment methods:; - Assessed at 5.9y of age (Median, 95% range: 5.5, 6.6); - [underlined: BP:] SBP, DBP; Measured in quadruplicate | SFAs; [underlined: SBP,] mmHg, Beta (95% CI); <13.3 g/d (ref); 13.3-16.5 g/d: 0.05 (−0.63, 0.72); >16.5 g/d: 0.29 (−0.39, 0.96); p-trend: 0.26; [underlined: DBP,] mmHg, Beta (95% CI); <13.3 g/d (ref); 13.3-16.5 g/d: 0.33 (−0.24, 0.89); >16.5 g/d: 0.10 (−0.47, 0.67); p-trend: 0.27; MUFAs; [underlined: SBP,] mmHg, Beta (95% CI); <11.5 g/d (ref); 11.5-14.6 g/d: 0.27 (−0.41, 0.94); >14.6 g/d: 0.65 (−0.02, 1.33); p-trend: 0.15; [underlined: DBP,] mmHg, Beta (95% CI); <11.5 g/d (ref); 11.5-14.6 g/d: 0.40 (−0.18, 0.96); >14.6 g/d: 0.39 (−0.17, 0.96); p-trend: 0.20; PUFAs; [underlined: SBP,] mmHg, Beta (95% CI); <7.0 g/d (ref); 7.0-8.6 g/d: 0.39 (−0.28, 1.06); >8.6 g/d: 0.26 (−0.41, 0.93); p-trend: 0.14; [underlined: DBP,] mmHg, Beta (95% CI); <7.0 g/d (ref); 7.0-8.6 g/d: 0.14 (−0.42, 0.70); >8.6 g/d: 0.10 (−0.46, 0.66); p-trend: 0.24 | Key confounders [underlined: NOT] accounted for: Family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity, SES (maternal education), TEI, physical activity.; Additional model adjustments: Smoking during pregnancy, birth weight, current child BMI; Limitations:; - Not all key confounders accounted for; - 45% attrition without information on whether non-responders differed from responders; - No preregistered statistical analysis plan; Funding sources:; Erasmus Medical Center, Rotterdam; Erasmus University, Rotterdam; Dutch Ministry of Health, Welfare, and Sport; Netherlands Organization for Health Research and Development
Stroobant, 2017 (https://www.ncbi.nlm.nih.gov/pubmed/28122928) ^33^; PCS, Generation R, Netherlands; Baseline N=5,088 Analytic N=2,967 (Attrition: 42%); Participant characteristics at baseline:; - Age: Median=12.9mo, 95% range: 12.2, 18.9; - Sex (female): 51.3%; - Race/ethnicity: Dutch ethnic background, 68.8%; - SES: Maternal educational level, None or primary education 5.5%, Middle school or <4y high school 36.0%, Higher education 58.6%; Monthly household income, <€1400 13.9%, €1400-2200 19.4%, >€2200 66.6%; - Anthropometry: Maternal BMI, Median=23.5, 95% range:18.8, 35.3; Fat intake at baseline, Mean (SD):; - SFA: 11.5% (3.6%) of energy; - MUFA: 9.8% (3.1%) of energy; - PUFA: 5.5% (1.5%) of energy; Blood lipids and BP at baseline:; - NR; Summary of findings:; Consumption of SFA, MUFA, or PUFA at the expense of CHO or protein, or consumption of MUFA or PUFA at the expense of SFA at ~13mo of age was not associated with blood pressure, and non-fasting total, LDL, or HDL cholesterol, or triglycerides at 6y of age. | Exposures:; - SFAs (continuous; per 5% energy); - Replacement of CHO; - Replacement of protein; - MUFAs (continuous; per 5% energy); - Replacement of CHO; - Replacement of SFA; - Replacement of protein; - PUFAs (continuous; per 5% energy); - Replacement of CHO; - Replacement of SFA; - Replacement of protein; [underlined: Diet assessment method and timing]:; - Self-administered, validated 211-item FFQ completed by parents/caregivers; - Assessed at baseline; Outcomes and assessment methods:; - Assessed at 6.0y of age (Median, 95% range: 5.7, 6.6); - [underlined: BP:] SBP, DBP; Measured in quadruplicate; Converted to age and sex adjusted SD scores; - [underlined: Non-fasting blood lipids:] TC, LDL, HDL, Triglycerides; Converted to age and sex adjusted SD scores | SFAs replacing CHO; [underlined: SBP,] SD score, Beta (95% CI); CHO: 0.074 (−0.065, 0.214); [underlined: DBP,] SD score, Beta (95% CI); CHO: 0.073 (−0.063, 0.209); [underlined: HDL,] SD score, Beta (95% CI); CHO: 0.043 (−0.119, 0.205); [underlined: Triglycerides,] SD score, Beta (95% CI); CHO: −0.073 (−0.236, 0.089); [underlined: TC & LDL]: NS, Data NR; MUFAs replacing CHO or SFA; [underlined: SBP,] SD score, Beta (95% CI); CHO: −0.065 (−0.241, 0.110); SFA: −0.139 (−0.443, 0.164); [underlined: DBP,] SD score, Beta (95% CI); CHO: −0.132 (−0.303, 0.039); SFA: −0.205 (−0.501, 0.091); [underlined: HDL,] SD score, Beta (95% CI); CHO: −0.010 (−0.217, 0.197); SFA: −0.053 (−0.408, 0.302); [underlined: Triglycerides,] SD score, Beta (95% CI); CHO: 0.028 (−0.179, 0.235); SFA: 0.102 (−0.253, 0.457); [underlined: TC & LDL]: NS, Data NR; PUFAs replacing CHO or SFA; [underlined: SBP,] SD score, Beta (95% CI); CHO: 0.109 (−0.053, 0.272); SFA: 0.035 (−0.124, 0.194); [underlined: DBP,] SD score, Beta (95% CI); CHO: 0.121 (−0.037, 0.272); SFA: 0.048 (−0.107, 0.203); [underlined: HDL,] SD score, Beta (95% CI); CHO: 0.053 (−0.138, 0.245); SFA: 0.010 (−0.178, 0.197); [underlined: Triglycerides,] SD score, Beta (95% CI); CHO: −0.038 (−0.230, 0.154); SFA: 0.035 (−0.152, 0.223); [underlined: TC & LDL]: NS, Data NR; Replacement of protein with SFA, MUFA, or PUFA; No associations between type of fat and blood lipids or BP (Data NR) | Key confounders [underlined: NOT] accounted for: Family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity, SES (maternal education, household income), TEI, physical activity (screen time, playing sports).; Additional model adjustments: Energy from protein, energy from all types of fat (substitution of CHO), energy from CHO and all types of fat except SFA (substation of SFA), parity, prenatal alcohol intake, prenatal smoking, maternal BMI, maternal age, breastfeeding, birth weight.; Limitations:; - Not all key confounders accounted for; - 42% attrition without information on whether non-responders differed from responders; - No preregistered statistical analysis plan; Funding sources:; Erasmus Medical Center, Rotterdam; Erasmus University, Rotterdam; Dutch Ministry of Health, Welfare, and Sport; Netherlands Organization for Health Research and Development
Harris, 2017 (https://www.ncbi.nlm.nih.gov/pubmed/28208667) ^9^; PCS, GINIplus and LISAplus, Germany; Baseline N=5,078 Analytic N=1,398 (Attrition: 72%); Participant characteristics at baseline:; - Age: Median=10.2y (IQR: 10.1, 10.3); - Sex (female): 49%; - Race/ethnicity: NR; - SES: Parental education (high), 71.3%; - Anthropometry: BMI, Median=16.7 (IQR: 15.6, 18.4); Fat intake at baseline, Median (IQR):; - SFA (%E): 12.6 (10.9, 14.7); - MUFA (%E): 10.7 (9.3, 12.3); - N-3 PUFA (%E): 0.54 (0.49, 0.62); - N-6 PUFA (%E): 3.7 (3.2, 4.3); Blood lipids, BP at baseline, Median (IQR):; - LDL (mmol/L): 2.1 (1.7, 2.5); - HDL (mmol/L): 1.2 (1.1, 1.4); - Triglycerides (mmol/L): 1.2 (0.9, 1.6); Summary of findings:; Higher intake of SFA at 10y of age was associated with decreases in triglycerides from 10y to 15y of age, but was not associated with change in LDL or HDL cholesterol. Consumption of MUFA, N-3 PUFA, and N-6 PUFA at 10y were not associated with change in LDL and HDL cholesterol or triglycerides. Replacement of SFA consumption with either MUFA, N-3 PUFA, N-6 PUFA, or carbohydrate consumption was not associated with change in blood lipids except for two sex-stratified analyses: replacement of SFA consumption with carbohydrate consumption in females was associated with higher LDL cholesterol and triglycerides. | Exposures:; - SFA (continuous; per IQR increase in %E); - MUFA (continuous; per IQR increase in %E); - N-3 PUFA (continuous; per IQR increase in %E); - N-6 PUFA (continuous; per IQR increase in %E); - Replacement of SFA (continuous; per IQR increase in %E from substituting FA or CHO):; - MUFA; - N-3 PUFA; - N-6 PUFA; - CHO; [underlined: Assessment method and timing]:; - Self-administered, validated 80-item FFQ; - Assessed at baseline (10y); Outcomes and assessment methods:; - Assessed at baseline (10y) and 15y of age; - [underlined: Blood lipids:] TC, LDL, HDL, triglycerides (17% fasted at 10y, 46.4% fasted at 15y) | Change in blood lipids from 10y-15y; SFAs; [underlined: LDL,] mmol/L, Beta (95% CI); −0.36 (−0.075, 0.003), p=0.068; [underlined: HDL,] mmol/L, Beta (95% CI); 0.005 (−0.017, 0.027), p=0.638; [underlined: Triglycerides,] mmol/L, Beta (95% CI); −0.38 (−0.75, −0.001), p=0.042; MUFAs; [underlined: LDL,] mmol/L, Beta (95% CI); −0.011 (−0.048, 0.025), p=0.534; [underlined: HDL,] mmol/L, Beta (95% CI); 0.011 (−0.009, 0.031), p=0.297; [underlined: Triglycerides,] mmol/L, Beta (95% CI); −0.012 (−0.046, 0.023), p=0.503; N-3 PUFAs; [underlined: LDL,] mmol/L, Beta (95% CI); −0.027 (−0.057, 0.003), p=0.082; [underlined: HDL,] mmol/L, Beta (95% CI); 0.005 (−0.012, 0.022), p=0.540; [underlined: Triglycerides,] mmol/L, Beta (95% CI); 0.000 (−0.028, 0.029), p=0.981; N-6 PUFAs; [underlined: LDL,] mmol/L, Beta (95% CI); −0.003 (−0.034, 0.028), p=0.849; [underlined: HDL,] mmol/L, Beta (95% CI); 0.016 (−0.002, 0.033), p=0.074; [underlined: Triglycerides,] mmol/L, Beta (95% CI); 0.009 (−0.021, 0.038), p=0.559; Results were similar when stratified by sex. See Harris, 2017 for more detail.; Change in blood lipids from 10y-15y; Replacement of SFA with MUFA, PUFA, or CHO; [underlined: LDL,] mmol/L, Beta (95% CI); MUFA: −0.034 (−0.082, 0.014), p=0.163; n-3 PUFA: −0.026 (−0.063, 0.012), p=0.179; n-6 PUFA: 0.017 (−0.021, 0.054), p=0.384; CHO: 0.060 (−0.004, 0.123), p=0.064; CHO-females: 0.125 (0.021, 0.229), p=0.019; CHO-males: 0.012 (−0.064, 0.088), p=0.755; [underlined: HDL,] mmol/L, Beta (95% CI); MUFA: 0.002 (−0.025, 0.029), p=0.894; n-3 PUFA: −0.003 (−0.024, 0.018), p=0.775; n-6 PUFA: 0.016 (−0.005, 0.038), p=0.129; CHO: −0.001 (−0.037, 0.034), p=0.947; CHO-females: −0.004 (−0.060, 0.052), p=0.891; CHO-males: 0.000 (−0.045, 0.045), p=0.991; [underlined: Triglycerides,] mmol/L, Beta (95% CI); MUFA: −0.041 (−0.086, 0.005), p=0.081; n-3 PUFA: 0.002 (−0.034, 0.037), p=0.916; n-6 PUFA: 0.018 (−0.018, 0.054), p=0.324; CHO: 0.057 (−0.003, 0.117), p=0.063; CHO-females: 0.098 (0.020, 0.176), p=0.014; CHO-males: 0.020 (−0.069, 0.108), p=0.663; Results for replacement of SFA with MUFA or PUFA were similar when stratified by sex. See Harris, 2017 for more detail. | Key confounders [underlined: NOT] accounted for: Race/ethnicity, physical activity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (parental education), TEI.; Additional model adjustments: Study region, BMI, screen-time at 10y, fasting status at blood sampling, lipid concentration at 10y, pubertal onset, all energy bearing nutrients except SFA (replacement models); Limitations:; - Not all key confounders accounted for; - Did not control for GINIplus intervention group; - 72% attrition with no information on bias due to loss to follow-up; - No preregistered statistical analysis plan; Funding sources:; Federal Ministry for Education, Science, Research and Technology; Helmholtz Zentrum Munich; Research Institute at Marien-Hospital Wesel; LMU Munich; TU Munich; IUF-Leibniz Research Institute for Environmental Medicine at the University of Dusseldorf; Federal Ministry for Environment; Helmholtz Centre for Environmental Research; Commission of the European Communities, the 7^th^ Framework Program: MeDALL project; Mead Johnson; Nestle
Williams, 2008 (https://www.ncbi.nlm.nih.gov/pubmed/18174786) ^37^; PCS, The Healthy Start Project, U.S.; Baseline N~741, Analytic N=519 (Attrition: 30%); Participant characteristics at baseline:; - Children enrolled in Head Start preschools; - Age: Mean 3.9y, SD=1.8y; - Sex (female): NR; - Race/ethnicity: 40% African American, 40% Hispanic; - SES: 90% families with annual income below the poverty line; - Anthropometry: NR; Fat intake at baseline, Mean:; - SFA (%E): ~11.9; - MUFA (%E): ~11.2; - PUFA (%E): ~5.5; - Cholesterol (mg): ~176; Blood lipids at baseline: NR; Summary of findings:; SFA and MUFA intake in children at 3.9 years was not significantly associated with triglycerides or total and HDL cholesterol at 8 years. | Exposures:; - SFA (continuous; %E); - MUFA (continuous; %E); [underlined: Diet assessment method and timing]:; - Direct observation/plate waste measures during school and food record and telephone interviews with primary adult food provider to capture outside school intake over 24h period (validated and reliable); - Assessed at baseline (3.9y); Outcomes and assessment methods:; - Assessed at 4y follow-up; - [underlined: Non-fasting blood lipids:] TC, HDL, triglycerides; Continuous and by category (TC and HDL only) | SFA; [underlined: TC]; Continuous outcome: P>0.05; Intake by category (normal vs borderline vs high): P>0.05; [underlined: HDL]; Continuous outcome: P>0.05; Intake by category (desirable vs borderline low vs low): P>0.05; [underlined: Trig]; Continuous outcome: P>0.05; MUFA; [underlined: TC]; Continuous outcome: P>0.05; Intake by category (normal vs borderline vs high): P>0.05; [underlined: HDL]; Continuous outcome: P>0.05; Intake by category (desirable vs borderline low vs low): P>0.05; [underlined: Trig]; Continuous outcome: P>0.05 | Key confounders [underlined: NOT] accounted for: SES, TEI, physical activity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, race/ethnicity; Additional model adjustments: Change in BMI; Limitations:; - Did not account for all key confounders; - Did not account for intervention site (co-exposure) in analyses; - No preregistered statistical analysis plan; Funding sources:; NIH
Khalil, 2017 (https://www.ncbi.nlm.nih.gov/pubmed/27919542) ^12^; PCS, Lifeways Cross-Generation Cohort Study, Ireland; Baseline N=1026 Analytic N=75 (Attrition: 93%); Participant characteristics at baseline:; - Age: ~5y; - Sex (female): 56%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI, Mean=16.96, SD=1.64; Fat intake at baseline:; - NR; Blood lipids and BP at baseline:; - NR; Summary of findings:; Consumption of SFAs, MUFAs, or PUFAs at 5y of age was not correlated with HDL cholesterol at 9y of age | Exposures:; - SFA (continuous; g); - MUFA (continuous; g); - PUFA (continuous; g); [underlined: Assessment method and timing]:; - Self-administered, 52-item FFQ completed by the mother; - Assessed at baseline (5y); Outcomes and assessment methods:; - Assessed at follow-up (9y); - [underlined: Non-fasting blood lipids:] HDL | SFAs; [underlined: HDL,] Pearson’s correlation; r=0.208, p=0.080; MUFAs; [underlined: HDL,] Pearson’s correlation; r=0.151, p=0.207; PUFAs; [underlined: HDL,] Pearson’s correlation; r=-0.076, p=0.524 | Key confounders [underlined: NOT] accounted for: Sex, age, Race/ethnicity, SES, physical activity, family history of CVD or diabetes; Key confounders accounted for: TEI; Additional model adjustments: None; Limitations:; - Not all key confounders accounted for; - FFQ was not validated; - No information provided on how sub-group with blood lipids was assembled; - No preregistered statistical analysis plan; Funding sources:; Health Research Board of the Republic of Ireland
Altwaijri, 2009 (https://www.ncbi.nlm.nih.gov/pubmed/19524158) ^1^; PCS, Project Heart Beat!, U.S.; Baseline N=678 Analytic N=NR (Attrition: NR%); Participant characteristics at baseline:; - Age: 8y, 11y, and 14y; - Sex (female): 49.1%; - Race/ethnicity: 20.1% Black; - SES: NR; - Anthropometry: NR; Fat intake at baseline: NR; Blood lipids at baseline: NR; Summary of findings:; In children and adolescents aged 8-18y of age, SFA, MUFA, and PUFA intake was not associated with total cholesterol. Greater cholesterol intake was associated with higher total cholesterol. When controlling for sexual maturation, dietary cholesterol intake was only associated with total cholesterol levels in boys. | Exposures:; - SFA (continuous; g); - MUFA (continuous; g); - PUFA (continuous; g); - Cholesterol intake (continuous; mg); [underlined: Diet assessment method and timing]:; - Validated, semi-quantitative, 137-item FFQ (representing previous week’s intake) administered by trained personnel; - Assessed at baseline and annually for 4y; Outcomes and assessment methods:; - Assessed at baseline and annually for 4y; - [underlined: Fasting blood lipids:] TC | SFA; [underlined: TC], mg/dL, Beta (SE); Data NR, P>0.05; MUFA; [underlined: TC], mg/dL, Beta (SE); Data NR, P>0.05; PUFA; [underlined: TC], mg/dL, Beta (SE); Data NR, P>0.05; Cholesterol; [underlined: TC], mg/dL, Beta (SE); 0.012 (0.005), P=0.013; Controlling for sexual maturation:; Female: 0.009 (0.007), P=0.230; Male: 0.014 (0.007), P=0.047 | Key confounders [underlined: NOT] accounted for: SES, TEI, physical activity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity.; Additional model adjustments: BMI, sexual maturation ([underlined: only] analysis of dietary cholesterol); Limitations:; - Did not account for all key confounders; - No information provided on missing data; - No preregistered statistical analysis plan; Funding sources:; NHLBI; CDC/Southwest Center for Prevention Research; Compaq Computer Corporation; UT Health Science Center at Houston, School of Public Health; USDA
Boreham, 1999 (https://www.ncbi.nlm.nih.gov/pubmed/10823742) ^3^; PCS, Young Hearts Project, U.K. (Northern Ireland); Baseline N=509 Analytic N=459 (Attrition: 10%); Participant characteristics at baseline:; - Age: ~12y; - Sex (female): 51%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI, Mean~19; Fat intake at baseline (12y), Mean (SD):; - PUFA:SFA ratio: Boys, 0.36 (0.15); Girls, 0.42 (0.17); - Cholesterol (mg/mJ/d): Boys, 18.7 (9.7); Girls, 17.8 (9.2); Fat intake at 15y, Mean (SD):; - PUFA:SFA ratio: Boys, 0.42 (0.18); Girls, 0.46 (0.21); - Cholesterol (mg/mJ/d): Boys, 17.2 (8.1); Girls, 15.4 (9.0); Blood lipids and BP at baseline, Mean:; - TC (mmol/L): ~4.65; - HDL (mmol/L): ~1.39; - SBP (mmHg): ~111; - DBP (mmHg): ~69; Summary of findings:; In adolescents, the PUFA:SFA intake ratio at 12 and 15y of age was not associated with total and HDL cholesterol, or blood pressure. In boys, cholesterol intake was not associated with total and HDL cholesterol, or blood pressure. In girls, greater cholesterol intake was associated with lower HDL cholesterol. | Exposures:; - PUFA:SFA ratio (continuous); - Cholesterol (continuous; mg/mJ/d); [underlined: Assessment method and timing]:; - Diet history with open-ended interview using photographic atlas to determine portion size; - Assessed at baseline (12y) and 15y of age; Outcomes and assessment methods:; - Assessed at baseline (12y) and 15y of age; - [underlined: Non-fasting blood lipids:] TC, HDL; - [underlined: BP:] SBP and DBP; measured in duplicate | PUFA:SFA ratio; [underlined: TC], Standardized beta (SE); Boys and Girls: Data NR, P>0.05; [underlined: HDL], Standardized beta (SE); Boys and Girls: Data NR, P>0.05; [underlined: SBP], Standardized beta (SE); Boys and Girls: Data NR, P>0.05; [underlined: DBP], Standardized beta (SE); Boys and Girls: Data NR, P>0.05; Cholesterol; [underlined: TC], Standardized beta (SE); Boys and Girls: Data NR, P>0.05; [underlined: HDL], Standardized beta (SE); Boys: Data NR, P>0.05; Girls: −0.09 (0.04), P=0.042; [underlined: SBP], Standardized beta (SE); Boys and Girls: Data NR, P>0.05; [underlined: DBP], Standardized beta (SE); Boys and Girls: Data NR, P>0.05 | Key confounders [underlined: NOT] accounted for: Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, SES, TEI, physical activity,; Additional model adjustments: Smoking, sexual maturation, vitamin C intake, carbohydrate (%E), total fat (%E); Limitations:; - Did not account for all key confounders; - Validity or reliability of diet history unknown; - No preregistered statistical analysis plan; Funding sources:; Northern Ireland Chest, Heart and Stroke Association; British Heart Foundation; Wellcome Trust
Masquio, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/25296762) ^17^; PCS, Brazil (Unnamed cohort); Baseline N=77 Analytic N=60 (Attrition: 12%); Participant characteristics at baseline:; - Adolescents with obesity participating in 1 year of interdisciplinary therapy for weight loss; - Age: Mean~16.8y; - Sex (female): NR; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI, Mean~36.9; Fat intake at baseline, Mean:; - SFA: ~18.9g; ~9.%E; - Participants with greater reductions in SFA intake had significantly higher SFA intake at baseline; Blood lipids and BP at baseline, Mean:; - TC (mg/dL): ~168; - LDL (mg/dL): ~105; - HDL (mg/dL): ~44; - Mean BP (mmHg): ~94; Summary of findings:; In adolescents with obesity participating in 1 year of interdisciplinary therapy, tertile of change in SFA intake was not associated with change in blood lipids or blood pressure. Continuous change in SFA intake was associated with change in total and LDL cholesterol. | Exposures:; - Change in SFA intake (categorical; tertiles); - T1 (n=20): Increase or low reduction in SFA (<3.68g); - T2 (n=20): Moderate reduction in SFA (3.8-13.67g); - T3 (n=20): High reduction in SFA (>13.67g); - Change in SFA intake (continuous; g); [underlined: Assessment method and timing]:; - Non-consecutive 3 day dietary record completed by adolescent with help from parents; - Assessed at baseline and 1y follow-up; Outcomes and assessment methods:; - Assessed at baseline and 1y follow-up; - [underlined: Fasting blood lipids:] TC, LDL, HDL; - [underlined: BP:] Mean BP | Change in blood lipids or BP; [underlined: TC,] mg/dL; T1 vs T2, T1 vs T3, T2 vs T3: All P>0.05; Continuous: B=0.31, 95% CI: 0.06, 0.56), P=0.02; [underlined: LDL,] mg/dL; T1 vs T2, T1 vs T3, T2 vs T3: All P>0.05; Continuous: B=0.27, 95% CI: 0.01, 0.53), P=0.04; [underlined: HDL,] mg/dL; T1 vs T2, T1 vs T3, T2 vs T3: All P>0.05; [underlined: Mean BP,] mmHg; T1 vs T2, T1 vs T3, T2 vs T3: All P>0.05 | Key confounders [underlined: NOT] accounted for: Sex, race/ethnicity, SES, TEI, physical activity, family history of CVD or diabetes.; Key confounders accounted for: Age.; Additional model adjustments: Visceral fat (analyses of continuous change in SFA intake only); Limitations:; - Do not account for all key confounders; - Only children who complied with interdisciplinary therapy (>75% attendance) selected for study; - Three day dietary record unvalidated; - All participating in interdisciplinary therapy for weight loss during study period; - No preregistered statistical analysis plan; Funding sources:; CNPq; CAPES; UNIFESP; AFIP; CEPE; CEMSA
Quivers, 1992 (https://www.ncbi.nlm.nih.gov/pubmed/1579405) ^27^; PCS, U.S. (Unnamed cohort); Baseline N=NA Analytic N=32 (Attrition: NA%); Selected from 259 who met blood lipid criteria and participated for ≥90d; Participant characteristics at baseline:; - Children with LDL cholesterol ≥110 mg/dL enrolled in the Cardiovascular Health Clinic for the Young prescribed National Cholesterol Education Program Step 1 Diet; - Age: 2-16y; - Sex (female): 50%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: NR; Fat intake at baseline, Median (SD):; - SFA (%E): 9.03 (2.34); - PUFA (%E): 4.24 (2.52); - Cholesterol (mg/d): 132.46 (63.78); Blood lipids at baseline, Median (SD):; - TC (mg/dL): 201.84 (31.18); - LDL (mg/dL): 147.69 (32.83); - HDL (mg/dL): 44.81 (7.79); - Triglycerides (mg/dL): 59.71 (23.60); Summary of findings:; In children with LDL cholesterol levels of at least 110mg/dL but normal triglycerides levels, reduction in grams of SFA intake (but not %E from SFA) was associated with decreased LDL cholesterol levels over ~1y of follow-up. This association was seen only when using Spearman correlations; no association was detected with Pearson correlations.Change in PUFA and dietary cholesterol intake were not associated with changes in LDL cholesterol. | Exposures:; - SFA (continuous; change from baseline to final; g and %E); - PUFA (continuous; change from baseline to final; g and %E); - Cholesterol (continuous; change from baseline to final; mg/d); [underlined: Assessment method and timing]:; - 5 day diet diaries completed by children and parents; - Assessed at baseline and final follow-up (~1.2y, range: ~0.4y to ~3.3y); Outcomes and assessment methods:; - Assessed at baseline and final follow-up (~1.2y, range: ~0.4y to ~3.3y); - [underlined: Blood lipids:] LDL (NR if fasting or non-fasting) | SFAs; [underlined: LDL,] Pearson correlation; Spearman Correlation; Change in blood lipids from baseline to final; g: 0.296, p=0.1; 0.396, p=0.025; %E: 0.015, p=0.936; 0.014, p=0.938; Rate of change (magnitude of change/time between baseline and final); g: 0.314, p=0.080; 0.494, p=0.004; %E: 0.048, p=0.793; 0.100, p=0.586; PUFAs; [underlined: LDL,] Pearson correlation; Spearman Correlation; Change in blood lipids from baseline to final; g: 0.297, p=0.099; 0.161, p=0.380; %E: 0.135, p=0.463; 0.070, p=0.703; Rate of change (magnitude of change/time between baseline and final); g: 0.437, p=0.013; 0.224, p=0.219; %E: 0.274, p=0.130; 0.126, p=0.492; Cholesterol; [underlined: LDL,] Pearson correlation; Spearman Correlation; Change in blood lipids from baseline to final; mg: 0.142, p=0.437; 0.123, p=0.501; Rate of change (magnitude of change/time between baseline and final); mg: 0.035, p=0.850; 0.091, p=0.619 | Key confounders [underlined: NOT] accounted for: Sex, age, race/ethnicity, SES, TEI, physical activity.; Key confounders accounted for: Family history of CVD or diabetes.; Additional model adjustments: None; Limitations:; - Not all key confounders accounted for; - Only selected participants who participated in clinic for at least 90 days; - 5 day diet diaries unvalidated; - No information on missing data; - No preregistered statistical analysis plan and relationships with most blood lipids NR; Funding sources:; NR

* Abbreviations: BP – blood pressure, CHO – carbohydrates, CI – confidence interval, DBP – diastolic blood pressure, HDL – HDL cholesterol, LDL – LDL cholesterol, NA – not applicable, NR – not reported, %E – percent energy, ref – reference group, SBP – systolic blood pressure, SD – standard deviation, SE – standard error, SES – socioeconomic status, TC – total cholesterol, TEI – total energy intake

† Statistically significant results bolded.

Table 3 Risk of bias for randomized controlled trials examining types of dietary fat consumed during childhood and cardiovascular disease intermediate and endpoint outcomes^*,,†^

| Randomization | Identification of participants – randomization | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result
Ballesteros, 2004,^2^ Crossover RCT | Some Concerns | | Low | Low | Low | Some Concerns
Denke, 2000,^5^ Crossover RCT | High | | Low | Some Concerns | Low | Some Concerns
Dorgan, 2011,^6^ RCT | Low | | Low | Low | Low | Some Concerns
Estevez-Gonzalez, 1998,^7^ Crossover RCT | Some Concerns | | Low | Low | Low | Some Concerns
Hakanen, 2010,^8^ RCT | Low | | Low | Some Concerns | Low | Some Concerns
Kaitosaari, 2003,^10^ RCT | Low | | Low | Some Concerns | Low | Some Concerns
Kaitosaari, 2006,^11^ RCT | Low | | Low | Some Concerns | Low | Some Concerns
Kwiterovich, 1995,^13^ RCT | Low | | Low | Low | Low | Low
Lapinleimu, 1995,^14^ RCT | Low | | Low | Low | Low | Some Concerns
Lehtovirta, 2018,^15^ RCT | Low | | Low | Low | Low | Some Concerns
Muros, 2015,^18^ Cluster RCT | Some Concerns | Some Concerns | Low | Low | Low | Some Concerns
Niinikoski, 2007,^22^ RCT | Low | | Low | Some Concerns | Low | Some Concerns
Niinikoski, 2009,^21^ RCT | Low | | Low | Some Concerns | Some Concerns | Some Concerns
Niinikoski, 2012,^23^ RCT | Low | | Low | Some Concerns | Low | Some Concerns
Nupponen, 2015,^24^ RCT | Low | | Low | Low | Low | Some Concerns
Obarzanek, 2001,^25^ RCT | Low | | Low | Low | Low | Some Concerns
Raitakari, 2005,^28^ RCT | Low | | Low | Low | Low | Some Concerns
Rask-Nissila, 2000,^29^ RCT | Low | | Low | Low | Low | Some Concerns
Routi, 1996,^30^ RCT | Low | | Low | Low | Low | Some Concerns
Simell, 2000,^31^ RCT | Low | | Low | Low | Low | Some Concerns
Simons-Morton, 1997,^32^ RCT | Low | | Low | Low | Low | Some Concerns
Vuholm, 2019,^36^ RCT | Low | | Low | Low | Low | Low

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

Table 4 Risk of bias for prospective cohort studies examining types of dietary fat consumed during childhood and cardiovascular disease intermediate and endpoint outcomes^*^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Altwaijri, 2009^1^ | Serious | Low | Low | Low | No information | Low | Moderate
Boreham, 1999^3^ | Serious | Low | Moderate | Low | Low | Low | Moderate
Cowin, 2001^4^ | Serious | Low | Serious | Low | Low | Low | Serious
Harris, 2017^9^ | Serious | Low | Low | Moderate | Moderate | Low | Moderate
Khalil, 2017^12^ | Serious | Low | Moderate | Low | No information | Low | Moderate
Magnussen, 2011^16^ | Serious | Low | Serious | Low | Moderate | Low | Moderate
Masquio, 2015^17^ | Serious | Moderate | Moderate | Moderate | Low | Low | Moderate
Ness, 2005^19^ | Serious | Moderate | Serious | Low | Moderate | Low | Moderate
Nicklas, 2002^20^ | Serious | Low | Low | Low | Moderate | Low | Moderate
Post, 1997^26^ | Serious | Low | Moderate | Low | Moderate | Low | Moderate
Quivers, 1992^27^ | Serious | Serious | Moderate | Low | No information | Low | Serious
Simons-Morton, 1997^32^ | Serious | Low | Low | Serious | Low | Low | Moderate
Stroobant, 2017^33^ | Serious | Low | Low | Low | Moderate | Low | Moderate
Twisk, 1996^34^ | Serious | Low | Moderate | Low | Moderate | Low | Moderate
van den Hooven, 2013^35^ | Serious | Low | Low | Low | Moderate | Low | Moderate
Williams, 2008^37^ | Serious | Low | Low | Moderate | Low | Low | Moderate

* Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

Table 5 Evidence examining types of dietary fat consumed by adults and cardiovascular disease intermediate outcomes (blood lipids)^*^

Study and Population Characteristics | Intervention, Comparator, Dietary intake | Outcomes & Results^†^ | Model adjustments & Study Limitations
RCT: Parallel Design
Abbaspour, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/31261928) ^38^; RCT parallel, U.S.; Baseline N=54 Analytic N=48 (Attrition: 11%); Participant characteristics at baseline: Adults (40% female) ~30y of age with overweight or obesity; Summary of findings:; Consuming mixed nuts for 8 weeks (which increased MUFA intake) did not significantly change blood lipids compared to consuming pretzels. | Intervention and comparator:; - Mixed nuts, 42.5g/d (n=24); - Sources: almonds, cashews, hazelnuts, pecans, Brazil nuts, macadamia nuts, pistachios, walnuts, and peanuts; - Pretzels, 69g/d (n=24); - Sources: NA; - Mixed nuts and pretzels were isocaloric (250 kcal); [underlined: Duration of intervention:] 8 wk; [underlined: Compliance:] Monitored via 24h recalls at baseline, 4wk, and 8wk; Encouraged via weekly text reminders; [underlined: Total diet intake at 8 wk for Nuts vs Pretzels, Mean (SD), %E:]; SFA: 12.2 (3.8) vs 10.4 (2.9), P=NS; MUFA: 18.2 (7.0) vs 11.8 (3.6), P<0.05; PUFA: 10.2 (3.1) vs 8.3 (3.1), P=NS; Cholesterol (g/d): 391 (286) vs 329 (171), P=NS; Other components of diet differed significantly: Total fat (higher in Nuts), CHO (lower in Nuts), vitamin E and copper (higher in Nuts) | Outcomes and assessment methods:; Fasting blood lipids: Measured at baseline, 4wk, and 8 wk; Repeated measures ANOVA (Group*Time); [underlined: TC], mmol/L, Baseline, 4wk, 8wk; Nuts vs Pretzels: All P=NS; [underlined: LDL], mmol/L, Baseline, 4wk, 8wk; Nuts vs Pretzels: P=NS; [underlined: HDL], mmol/L, Baseline, 4wk, 8wk; Nuts vs Pretzels: P=NS; [underlined: Triglycerides], mmol/L, Baseline, 4wk, 8wk; Nuts vs Pretzels: P=NS | Model adjustments:; Baseline blood lipid; Limitations:; - Allocation sequence was not concealed; - No information on adherence; - No preregistered statistical analysis plan; Funding sources:; AHA
Akrami, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/29229363) ^41^; RCT parallel, Iran; Baseline N=60 Analytic N=52 (Attrition: 13%); Participant characteristics at baseline: Participants (37% female) aged mean 48 years with metabolic syndrome; Summary of findings:; In adults with metabolic syndrome, consumption of flaxseed oil (higher in ALA), compared to sunflower seed oil (higher in LA), did not result in significant differences in total blood, LDL, HDL cholesterol, or triglycerides. | Intervention and comparator:; - Cold-pressed Flaxseed oil (n=26): 25 mL/day – SFA 15%, MUFA 28%, PUFA 58%, Oleic acid 27%, LA: 16%, ALA 41%; - Cold-pressed Sunflower seed oil (n=26): 25 mL/day - SFA 14%, MUFA 28%, PUFA 58%, Oleic acid 28%, LA 58%, ALA0%; - Participants instructed to add test oils to their cold food or as salad dressings; [underlined: Duration of intervention:] 7 wk (3 week run-in); [underlined: Compliance:] measured at 2 and 6 wk follow-up; [underlined: Dietary intake for Flaxseed vs Sunflower seed oil at end of intervention, Mean (SD), %E:]; SFA: 7.5 (0.8) vs 7.6 (0.6), P=NS; MUFA: NR; PUFA: 17.3 (0.9) vs 16.5 (0.9), P=0.006; n-3 PUFA: 15.2 (1.2) vs 0.8 (0.1), P<0.001; Cholesterol: NR; Other components of diet differed significantly: None | Outcomes and assessment methods:; Fasting blood lipids: Measured at baseline and 7wk follow-up; Comparing difference in change between groups; [underlined: TC], mg/dL; Flaxseed vs sunflower seed oil: NS; [underlined: LDL], mg/dL; Flaxseed vs sunflower seed oil: NS; [underlined: HDL], mg/dL; Flaxseed vs sunflower seed oil: NS; [underlined: Triglycerides], mg/dL; Flaxseed vs sunflower seed oil: NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - No information on compliance; - No information on whether missing data was different between groups; - No preregistered statistical analysis plan; Funding sources:; Research Vice-chancellor of Shiraz University of Medical Sciences
Annuzzi, 2014 (https://www.ncbi.nlm.nih.gov/pubmed/24368433) ^44^; RCT parallel, Italy; Baseline N=86, Analytic N=78 (Attrition: 9%); Participant characteristics at baseline: Adults ~55y of age with overweight or obesity, high waist circumference, and at least one additional component of metabolic syndrome.; Summary of findings:; In adults with overweight or obesity, high waist circumference, and at least one other component of metabolic syndrome, consumption of a diet high in n-3 PUFA (primarily EPA/DHA from fish) did not significantly change blood lipids compared to a diet lower in n-3 PUFA. | Intervention and comparators:; - High long chain n-3 PUFA: ~1.5%E from n-3 PUFA (primarily EPA/DHA); - Source: Anchovies, Dentex (type of predatory fish) and/or Salmon; - Low polyphenol group (~363 mg/d): n=19; - High polyphenol group (~2861 mg/d): n=19; - Low n-3 PUFA: ~0.5%E from n-3 PUFA; - Low polyphenol group (~365 mg/d): n=20; - High polyphenol group (~2903 mg/d): n=20; - All meals provided by researchers; - All diets were weight maintaining; - Macronutrient distribution same across all groups (50.7%E carbohydrates, 15.7%E protein, 33.6% total fat); [underlined: Duration of intervention:] 8 wk (3 wk run-in); [underlined: Compliance:] Evaluated via 7 day dietary records at baseline, 4wk, and 8wk; reinforced by phone calls every 2-3 days from study dietitians; Participants were compliant with study diets; [underlined: Diet composition for High n-3 PUFA vs Low n-3 PUFA, Mean, %E:]; SFA: ~7.3% vs ~7.2%, P=NS; MUFA: ~19.3% vs ~20.1%, P=NS; n-6 PUFA: ~2.7% vs ~3%, P=NS; n-3 PUFA: ~1.5% vs ~0.5%, P<0.0001; EPA: ~0.45% vs ~0.03%, P<0.0001; DHA: ~0.59% vs ~0.01%, P<0.0001; Cholesterol: ~197 mg/d vs ~185 mg/d, P=NS; Other components of diet differed significantly: None | Outcomes and assessment methods:; Fasting blood lipids: Assessed at baseline and 8wk; Comparing change in blood lipids between groups; [underlined: TC], mg/dL; High n-3 vs Low n-3: P=NS; n-3 by polyphenol interaction: P=NS; [underlined: LDL], mg/dL; High n-3 vs Low n-3: P=NS; n-3 by polyphenol interaction: P=NS; [underlined: HDL], mg/dL; High n-3 vs Low n-3: P=NS; n-3 by polyphenol interaction: P=NS; [underlined: Triglycerides], mg/dL; High n-3 vs Low n-3: P=NS; n-3 by polyphenol interaction: P=NS | Model adjustments:; Polyphenol group, polyphenol by n-3 group interaction, baseline blood lipid value; Limitations:; - No preregistered statistical analysis plan; Funding sources: European Community’s Seventh Framework Programme: Etherpaths Project; Foresid, Italian Society of Diabetology; Italian Diabetes Society; Food supplied by Lavazza, Nestle, Parmalat S.p.A., Zuegg S.p.A., Pompadour Te S.r.l., Coop. Nuovo Cilento s.c.r.l.
Baxheinrich, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22894911) ^47^; RCT parallel, Germany; Baseline N=95 Analytic N=81 (Attrition: 15%); Participant characteristics at baseline: Adults (68% female) with metabolic syndrome, ~51 years, BMI ~34, no CVD; Summary of findings:; Consumption of a rapeseed oil diet (high in ALA) versus olive oil diet (low in ALA), within a hypocaloric, low energy density dietary pattern for 26-weeks, resulted in a significant decrease in triglyceride levels, but no other significant between-group differences in lipids in persons with metabolic syndrome. Consumption of a rapeseed oil (30 g) and olive oil (30 g), replacing SFA with MUFA, significantly decreased total blood and LDL cholesterol and had no effect on HDL cholesterol. | Intervention and comparator:; - Rapeseed oil (RO) diet (30g/d oil plus 20g/d margarine), n=40; - Sources: Refined rapeseed oil and rapeseed-based commercial margarine (Types of fat NR); - High MUFA; [underlined: high ALA content]; - Olive oil (OO) diet (30g/d oil plus 20g/d margarine), n=41; - Sources: Refined olive oil and an olive oil-based margarine (Types of fat NR); - High MUFA; [underlined: low ALA content]; - Once a week OO was replaced by sunflower oil to compensate for low LA in OO; - All participants on hypoenergetic diet (energy deficiency of 2·0–3·3MJ) with low energy density (ED), 42%E carbohydrates, 20% protein, and 38% fat (SFA<10% and MUFA 18%).; - Participants received diet instruction and coaching from dietitians; [underlined: Duration of intervention:] 26 wk (~6 mo); [underlined: Compliance:] Good compliance based on diet records; however, 9 excluded (3 RO/6 OO) due to non-compliance; [underlined: Dietary intake for RO vs OO, Mean (SD):]; SFA: NS; MUFA: NS; PUFA (%E): 8.1 (1.9) vs 5.5 (0.9); P<0.001; ALA (g/day): 3.46 (0.84) vs 0.78 (0.17); P<0.001; LA (g/day): 10.8 vs 8.5, P=NS; No significant difference in energy, macronutrient, and fiber intake. | Outcomes and assessment methods:; Fasting blood lipids: Assessed at baseline and at 6 mo.; Difference in lipid values from baseline; [underlined: TC], mmol/l, mean difference; RO: −0.30; OO: −0.38; RO vs OO: P=NS; [underlined: LDL], mmol/l, mean difference; RO: −0.22; OO: −0.28; RO vs OO: P=NS; [underlined: HDL], mmol/l, mean difference; RO: NS; OO: NS; RO vs OO: P=NS; [underlined: Triglycerides], mmol/l, mean difference; RO: −0.45; OO: −0.20; RO VS OO: P=0.020 | Model adjustments:; None; Limitations:; - No information provided on randomization method; - Potential missing data bias due to not statistically accounting for missing data; - No preregistered statistical analysis plan; Funding sources:; Union for Promoting Oil and Protein Plants (UFOP); the International Foundation for the Promotion of Nutrition Research and Nutrition Education (ISFE)
Beavers, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/20521988) ^48^; RCT parallel, U.S.; Baseline N=33 Analytic N=32 (Attrition: 0%); Participant characteristics at baseline:; Healthy, physically active, postmenopausal women aged ~54 years, BMI ~26, no hormone replacement therapy, no smoking; Summary of findings:; Consumption of three servings per day of soy versus dairy milk had no significant effect on blood total, LDL and HDL cholesterol and triglycerides in physically active postmenopausal women. | Intervention and comparator:; - 3 servings (8.25 fl oz)/d vanilla soy milk (n=16); - 3 servings (8 fl oz)/d reduced fat dairy milk (n=16); [underlined: Duration of intervention:] 4 wk (2 wk run-in, no washout period); [underlined: Compliance:] 98% compliance, after removal on one non-compliant subject (defined as <80% consumption), assessed via compliance logs.; [underlined: Dietary intake soy vs dairy intervention at post-intervention, Mean (SD), g/day:]; SFA: 20.39 (13.56) vs 28.27 (8.68), P<0.05; MUFA: 16.76 (8.51) vs 20.06 (9.10), P: NS; PUFA: 13.47 (5.66) vs 8.72 (5.77), P: NS; Cholesterol (mg/d): 168.36 (97.38) vs 291.56 (105.15), P: NS; No other components of diet differed. | Outcomes and assessment methods:; Fasting blood lipids at the start and end of each diet phase; Blood lipid levels at follow-up; [underlined: TC], mg/dL; Soy vs dairy: P=NS; [underlined: LDL], mg/dL; Soy vs dairy: P=NS; [underlined: HDL], mg/dL; Soy vs dairy: P=NS; [underlined: Triglycerides], mg/dL; Soy vs dairy: P=NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - No preregistered statistical analysis plan; Funding sources:; White-Wave Foods, Inc.
Bergeron, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/31161217) ^49^; RCT parallel (low vs high SFA), crossover (sources), U.S.; Baseline N=177 Analytic N=113 (Attrition: 36%); Participant characteristics at baseline: Participants (55% White, ~20% Asian) 43 y with BMI ~26 and normal lipid concentrations; Summary of findings:; High SFA diet including sources from high-fat dairy products and butter, significantly increased total cholesterol, LDL cholesterol, but not HDL cholesterol and triglycerides.; Total blood cholesterol, LDL, and HDL cholesterol were significantly higher with red meat and white meat compared to nonmeat, independent of SFA content. There were no differences in blood lipids between red and white meat. | Intervention and comparator:; - Low SFA (~7%E), n=51; - Red meat: SFA: 8%E, MUFA 21%E, PUFA: 5% E, Cholesterol: 353 mg/day; - White poultry meat: SFA: 7%E, MUFA 18%E, PUFA: 6% E, Cholesterol: 424 mg/day; - Nonmeat: SFA: 7%E, MUFA 20%E, PUFA: 5% E, Cholesterol: 275 mg/day; - High SFA (~14%E): n=62, high-fat dairy products and butter; - Red meat: SFA: 13%E, MUFA 12%E, PUFA: 5% E, Cholesterol: 403 mg/day; - White poultry meat: SFA: 14%E, MUFA 13%E, PUFA: 5% E, Cholesterol: 473 mg/day; - Nonmeat: SFA: 13%E, MUFA 12%E, PUFA: 5% E, Cholesterol: 403 mg/day; [underlined: Duration of intervention:] 4 wk (2-7 wk washout); [underlined: Compliance:] menu checklists, grocery receipts, reported deviations from dietary instructions; “excellent” compliance; [underlined: Dietary intake for Intervention vs Control, Mean (SD), g/day:] NR | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 wk follow-up (after each diet); Blood lipid levels after each diet period; [underlined: TC], mmol/L, Mean (SE); Mean difference:; High - Low SFA: 0.22 (0.08), P=0.0002; Red meat - White meat: P=NS; Red meat - nonmeat: 0.18 (0.04), P<0.0001; White meat - nonmeat: 0.18 (0.04), P<0.0001; [underlined: LDL,] mmol/L, Mean (SE); Mean difference:; High - Low SFA: 0.23 (0.06), P=0.0003; Red meat - White meat: P=NS; Red meat - nonmeat: 0.16 (0.03), P<0.0001; White meat - nonmeat: 0.16 (0.03), P<0.0001; [underlined: HDL], mmol/L, Mean (SE); Mean difference:; High - Low SFA: P=NS; Red meat - White meat: P=NS; Red meat - nonmeat: 0.03 (0.01), P=0.007; White meat - nonmeat: 0.04 (0.01); P=0.0001; [underlined: Triglycerides], mmol/L, Mean (SE); Mean difference:; High - Low SFA: P=NS; Red meat - White meat: P=NS; Red meat - nonmeat: P=NS; White meat - nonmeat: P=NS | Model adjustments:; Dietary period; Limitations:; - Missing outcome data was unbalanced between groups; - No preregistered statistical analysis plan; Funding sources:; NHLBI; National Center for Advancing Translational Sciences; University of California, San Francisco Clinical & Translational Science Institute
Blesso, 2013 (https://www.ncbi.nlm.nih.gov/pubmed/23021013) ^52^; RCT parallel, U.S.; Baseline N=40 Analytic N=37 (Attrition: 8%); Participant characteristics at baseline: Adults (~66% female) ~52y of age with overweight or obesity and with metabolic syndrome; Summary of findings:; In adults with overweight or obesity and with metabolic syndrome following a CHO restricted diet, consumption of 3 eggs/d for 12 weeks (which increased cholesterol intake) did not significantly change blood lipids compared to consumption of an egg substitute devoid of dietary cholesterol and fat. | Intervention and comparator:; - Whole eggs (3 per day: 534 mg dietary cholesterol) while consuming a CHO restricted diet (25-30%E from CHO), n=20; - Egg substitute (0 mg dietary cholesterol, fat-free) while consuming a CHO restricted diet (25-30%E from CHO), n=17; - Participants instructed to avoid eating eggs outside of the dietary intervention; [underlined: Duration of intervention:] 12 wk; [underlined: Compliance:] Assessed via 5d dietary intake records at baseline, 6wk, and 12wk; [underlined: Dietary intake at 12 wk for Egg vs Control, Mean (SD), %E:]; SFA: NR; MUFA: NR; PUFA: NR; Cholesterol (mg/d): 740.8 (139.7) vs 213.4 (83.3), P<0.0001; Other components of diet differed significantly: Choline (higher in Egg group) | Outcomes and assessment methods:; Fasting blood lipids at baseline, 6wk, and 12wk; Time*Group interaction; [underlined: TC], mg/dL; Egg vs Control: P=NS; [underlined: LDL], mg/dL; Egg vs Control: P=NS; [underlined: HDL], mg/dL; Egg vs Control: P=NS; [underlined: Triglycerides], mg/dL; Egg vs Control: P=NS | Model adjustments:; None; Limitations:; - No information on randomization of allocation sequence; - No information on compliance; - No preregistered statistical analysis plan; Funding sources:; American Egg Board/Egg Nutrition Center
Bjermo, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22492369) ^50^; RCT parallel, HEPFAT, Sweden; Baseline N=67 Analytic N=61 (Attrition: 9%); Participant characteristics at baseline: Men and women were 51-63y, with abdominal diameter >25cm or waist circumference >88 cm (women) or >102 cm (men); no differences in BMI, lipids and cholesterol between groups at baseline.; Summary of findings:; Participants who were assigned to the PUFA diet had significantly greater decrease in total cholesterol compared to those who were assigned to the SFA diet for 10 weeks. | Intervention and comparator:; - PUFA diet (n=32) – n-6 LA; - Instructed to consume ~15% of energy as LA; - Sources: Scones (baked on sunflower oil), margarine, sunflower oil, sunflower seeds; - SFA diet (n=29); - Sources: scones (baked-on butter) and butter; [underlined: Duration of intervention:] 10 wk; [underlined: Compliance:] 3-day weighed food records; [underlined: Change in dietary intake from baseline during intervention for Intervention (PUFA diet) vs Control (SFA diet), Mean (SD), g/day:]; Total fat: Increased more for SFA diet than PUFA diet, P<0.01; SFA: Decreased in PUFA; Increased in SFA, Change between group, P<0.001; MUFA: NR; AA (20:4n-6): Change between group: P=NS; LA: Increased in PUFA diet, decreased in SFA diet, Change between group, P<0.001; PUFA: ALA (18:3n-6), Dihomo-gamma-linolenic acid (20:3n-6), AA (20:4n-6) did not differ between groups, P>0.36; Cholesterol: NR; Other components of diet differed significantly: Change in total fat was significantly different between groups (increased more for SFA diet); | Outcomes and assessment methods:; Fasting blood lipids at 10 wk; [underlined: TC], mmol/L, Mean (SD); Change (follow-up – baseline):; PUFA: −0.2 (0.4); SFA: 0.0 (0.5); P=0.01; [underlined: LDL], mmol/L, Mean (SD); PUFA vs SFA diet: NS; [underlined: HDL], mmol/L, Mean (SD); PUFA vs SFA diet: NS; [underlined: Triglycerides], mmol/L, Mean (SD); PUFA vs SFA diet: NS | Model adjustments:; Baseline values; Limitations:; - No information provided on randomization method; - Did not adjust for compliance in per protocol analyses; - No preregistered statistical analysis plan; Funding sources:; Swedish Council for Working Life and Social Research
Bladbjerg, 2011 (https://pubmed.ncbi.nlm.nih.gov/21320366) ^51^; RCT parallel, MUFObes trial, Denmark; Baseline=131 Analytic N=99 (Attrition: 24%); Participant characteristics at baseline: ~28y, Obese (BMI~31), 61% female, recent loss of ≥8% body weight, non-smokers, no regular medications; Summary of findings:; Consumption of a high MUFA diet, low fat diet or a control diet for 6 months to maintain weight loss, had no significant between-group differences in changes to blood lipids in overweight adults. | Intervention and comparators:; - High MUFA diet: Moderate (35-45%E) fat, high (>20%E) MUFA, and moderate (40-50%E in low-GI CHO, moderate (10-20%) protein (n=36); - High content of vegetable oils, whole-grain foods, nuts, and legumes; - Low fat diet: 20-30%E fat, high (55-65%E) in mixed GI CHO, moderate (10-20%E) protein (n=40); - Control diet (average Danish diet): Moderate (30-40%E) fat, high SFA (>15%E), moderate (45-55%E) in high-GI CHO, low (<3%) fiber, moderate (10-20%) protein (n=23); - Weight loss maintenance diets, all foods and beverages selected at study supermarket with feedback from dietitians and only these foods were to be consumed; [underlined: Duration of intervention:] 6 months (preceded by an 8- wk low energy (800-1000kcal/d) diet--only subjects who lost ≥8% body weight were randomized; followed by 3 week standardization diet similar to the control diet); [underlined: Compliance:] Monitored food selection, blood fatty acid analysis; compliance NR; [underlined: Dietary composition for High-MUFA, LF diet vs Control diet, Mean (95% CI)]:; Total fat: 38.4 (37.9, 39.0) vs 23.6 (23.1, 24.1) vs 32.1 (31.4, 32.7), P<0.001; SFA (%E): 7.1 (6.9, 7.4) vs 7.9 (7.6, 8.3) vs 15.1 (14.7, 15.5), P<0·001; MUFA (%E): 20.2 (19.8, 20.6) vs 8.4 (8.1, 8.6) vs 10.4 (10.0, 10.8), P<0·001; PUFA (%E): 7.8 (7.6, 8.1) vs 5.2 (5.1, 5.4) vs 4.0 (3.7, 4.3), P<0·001; CHO (%E): 43.3 (42.7, 43.9) vs 57.6 (57.0, 58.2) vs 49.8, (49.2, 50.5), P<0.001; Other components of diet that differed: Fiber, added sugar | Outcomes and assessment methods:; Fasting blood lipids: At baseline and at 6 months; Blood lipid levels at follow-up; [underlined: TC,] mmol/L; Between groups: NS; [underlined: LDL], mmol/L; Between groups: NS; [underlined: Triglycerides,] mmol/L; Between groups: NS; Subjects in all groups had a significant increase in BMI | Model adjustments:; None; Limitations:; - No information provided about diet compliance; - Potential bias from missing data; - Trial registration is retrospective; Funding sources:; HA Foundation, the Danish Heart Association, the Danish Diabetes Association, Centre for Advanced Food Research, the State Research Councils, and the Danish Pork Council foundations, associations and research councils
Bos, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/19692213) ^53^; RCT parallel, Netherlands; Baseline N=59 Analytic N=57 (Attrition: 3%); Participant characteristics at baseline: Participants (~58% female) between 40-65 years with mild abdominal obesity and slightly elevated total cholesterol and LDL cholesterol at baseline; Summary of findings:; Participants who consumed high SFA diet, compared to high MUFA diet with refined olive oil, had significantly higher total blood and LDL cholesterol. | Intervention and comparator:; - High MUFA diet (20%E MUFA), n=18 – refined olive oil; - High SFA diet (19%E SFA), n=19 – no food source reported; - Controlled-feeding trial; All meals provided to participants; 1 meal/d eaten under supervision of researchers; [underlined: Duration of intervention:] 8 wk (2 wk run-in on high SFA diet); [underlined: Compliance:] NR but indicates that participants had high compliance; [underlined: Dietary intake for High MUFA, and High SFA diets, Mean (SD), %E:]; [underlined: SFA:] 10.9 vs 19.2; [underlined: MUFA:] 20.3 vs 10.7; [underlined: PUFA:] 7.0 vs 5.4; [underlined: n-3 PUFA:] 0.6 vs 0.4; [underlined: n-6 PUFA:] 6.4 vs 5.0; Other components that differed between groups: None | Outcomes and assessment methods:; Fasting blood lipids at baseline and 8 wk follow-up; [underlined: TC], mmol/L, Difference, Mean (95% CI); MUFA (ref) vs SFA (MUFA-SFA): −0.41 (−0.74, −0.09) (greater decreases in MUFA than SFA); [underlined: LDL], mmol/L, Difference, Mean (95% CI); MUFA (ref) vs SFA (MUFA-SFA): −0.38 (−0.65, −0.11) (greater decreases in MUFA than SFA); [underlined: HDL], mmol/L, Difference, Mean (95% CI); MUFA vs SFA: NS; [underlined: Triglycerides], mmol/L, Difference, Mean (95% CI); MUFA vs SFA: NS | Model adjustments:; Baseline levels, gender, participation in clamp measurements; Limitations:; - No information on compliance; Funding sources:; Netherlands Heart Foundation; Dutch Diabetes Research Foundation; Unilever R&D
Chiu, 2014 (https://pubmed.ncbi.nlm.nih.gov/25332473) ^59^; RCT parallel, U.S.; Baseline N=174 Analytic N=158 (Attrition: 9%); Participant characteristics at baseline: Participants ~38 years with BMI ~33 without history of diabetes or CVD with small but significant differences in total cholesterol at baseline; Summary of findings:; Intake of high SFA from high-fat dairy (milk, cheese, yogurt, butter), compared to low SFA from low-fat dairy, did not alter TC, LDL, HDL cholesterol, and triglycerides. | Intervention and comparators:; - High SFA, high protein (n=32): SFA 15%E, MUFA 10%E, PUFA 7%, protein 30%E; - Source: High-fat dairy (milk, cheese, yogurt, butter); - Low SFA, high protein (n=36): SFA 7%E, MUFA 18%E, PUFA 7%, high protein 30%E; - Source: low-fat and non-fat dairy (milk, cheese, yogurt, butter); - High SFA, moderate protein (n=35): SFA 15%E, MUFA 20%E, PUFA 7%, protein 20%E; - Source: High-fat dairy (milk, cheese, yogurt, butter); - Low SFA, moderate protein (n=34): SFA (7%E), MUFA 29%E, PUFA 7%, protein 20%E; - Source: low-fat and non-fat dairy (milk, cheese, yogurt, butter); - Control (n=33); [underlined: Duration of intervention:] 4 wk; [underlined: Compliance:] 5-point compliance score based on weekly interviews, menu checklists, grocery receipts; 95% of participants had dietary compliance score of 4 or 5; [underlined: Dietary intake for high SFA vs low SFA:] NR | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 wk follow-up; Difference in change; [underlined: TC], mmol/L, Mean (SE); High vs low SFA: NS*; [underlined: LDL], mmol/L, Mean (SE); High vs low SFA: NS*; [underlined: HDL], mmol/L, Mean (SE); High vs low SFA: NS*; [underlined: Triglycerides], mmol/L, Mean (SE); High vs low SFA: NS*; *Inclusion of compliance score as a covariate did not significantly alter results | Model adjustments:; Sex; Limitations:; - No information provided on randomization method; - Baseline differences in total cholesterol; - No preregistered statistical analysis plan; Funding sources:; Dairy Management, Inc; National Center for Research Resources; National Center for Advancing Translational Sciences
Clayton, 2015 (https://pubmed.ncbi.nlm.nih.gov/25785868) ^61^; RCT parallel, U.S.; Baseline N=40, Analytic N=25 (Attrition: 37%); Participant characteristics at baseline: Recreationally active adults ~25y of age; Summary of findings:; Among young adults participating in resistance training, consumption of an egg based breakfast daily for 12 weeks (which increased cholesterol intake within group; between-group NR) did not significantly change blood lipids compared to consumption of a bagel based breakfast. | Intervention and comparator:; - Egg-based breakfast (2 eggs/d) while participating in resistance training (3d/wk), n=11; - Sources: eggs; - Bagel-based breakfast (9cm-diameter bagel/d) while participating in resistance training (3d/wk); Isoenergetic with egg-based breakfast, n=14; - Sources: NA; - Participants instructed not to eat eggs outside of the dietary intervention; [underlined: Duration of intervention:] 12 wk; [underlined: Compliance:] Assessed via 3-d food records at baseline, 6wk, and 12wk; [underlined: Dietary intake at 12wk for Intervention vs Control, Mean (SD), g/d:]; SFA: 24.61 (10) vs 26.29 (15), P=NR; MUFA: 10.96 (6) vs 12.34 (8), P=NR; PUFA: 4.26 (2) vs 6.09 (5), P=NR; Cholesterol (mg/d): 446.04 (117) vs 292.97 (290), P=NR; Other components of diet differed significantly: NR | Outcomes and assessment methods:; Fasting blood lipids: Measured at baseline, 6wk, and 12wk Repeated measures ANOVA; [underlined: TC], mg/dL; Egg vs Control: P=NS; [underlined: LDL], mg/dL; Egg vs Control: P=NS; [underlined: HDL], mg/dL; Egg vs Control: P=NS; [underlined: Triglycerides], mg/dL; Egg vs Control: P=NS | Model adjustments:; None; Limitations:; - No information on randomization of allocation sequence; - No information on compliance; - No information on whether missing data was different between groups; - No preregistered statistical analysis plan; Funding sources:; Egg Nutrition Council
de Souza, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/30086484) ^63^; RCT parallel, Brazil; Baseline N=60 Analytic N=46 (Attrition: 23%); Participant characteristics at baseline: Women 20-59y of age with overweight or obesity.; Summary of findings:; Women consuming 20g/d of baru almonds for 8 weeks, which increased MUFA intake, significantly increased HDL cholesterol relative to women consuming a baru-almond free diet. Almond intake did not have an effect on total or LDL cholesterol, or triglycerides. | Intervention and comparator:; - Baru almond-enriched diet (BAED), 20g/d daily (n=24); - Sources: Roasted almonds; - Baru almond-free diet (BAFD) (n=22); - Sources: maltodextrin; - Both groups received individualized prescription of normocaloric and isoenergetic diet; [underlined: Duration of intervention:] 8 wk; [underlined: Compliance:] Assessed via weekly phone calls, monthly consultations, and food records (NR); all participants completed the study; [underlined: Total dietary intake for BAED vs BAFD, Mean (SD), %E:]; SFA: 15.79 (8.74) vs 14.60 (5.92), P=NS; MUFA: 15.67 (8.36) vs 9.08 (4.11), P=0.04, Time by Diet: P=0.05; PUFA: 11.73 (8.48) vs 6.75 (2.86), P=0.00, Time by Diet: P=NS; Cholesterol: NR; Other components of diet differed significantly: Total fat and dietary fiber (higher in BAED) | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline and at end of 8 wk.; [underlined: TC], mg/dL; BAED vs BAFD: P=NS; Time by Diet: P=NS; [underlined: LDL], mg/dL; BAED vs BAFD: P=NS; Time by Diet: P=NS; [underlined: HDL], mg/dL, Mean (SD), wk0, wk8; BAED: 46.5 (8.98), 50.13 (9.40); BAFD: 44.73 (8.71), 43.54 (10.38); BAED vs BAFD: P=0.18; Time by Diet: P=0.04; [underlined: Triglycerides], mg/dL; BAED vs BAFD: P=NS; Time by Diet: P=NS | Model adjustments:; Baseline blood lipid value; Included when p<0.05: sequence and period.; Limitations:; - No preregistered statistical analysis plan; Funding sources: Foundation for Research Support of the State of Goias, Brazil
Dhillon, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/30044438) ^64^; RCT parallel, U.S.; Baseline N=80 Analytic N=73 (Attrition: 9%); Participant characteristics at baseline: Normolipidemic first year college students ~18y of age; mean BMI: 25.5; Summary of findings:; Young adults who consumed an almond snack daily for 8 weeks (increasing MUFA intake) had a smaller decrease in HDL cholesterol compared to young adults who consumed graham crackers. Almond intake did not have an effect on total or LDL cholesterol, or triglycerides. | Intervention and comparator:; - Almonds, 56.7g/d daily (n=38); - Sources: dry-roasted almonds; - Graham crackers, 77.5g/d (n=35); - Sources: graham crackers; [underlined: Duration of intervention:] 8 wk; [underlined: Compliance:] Assessed via direct observation of consumption on weekdays and via text message on weekends and school breaks; Snack consumed ~6 days per week, no differences between groups; [underlined: Total dietary intake at wk8 for Almond vs Graham cracker, Mean (SD), g/d:]; SFA: 22.2 (11.7) vs 19.2 (9.8), P=NS; MUFA: 31.8 (14.1) vs 22.0 (8.6), P=0.013,; PUFA: 20.1 (9.9) vs 15.2 (7.7), P=NS; Cholesterol: NR; Other components of diet differed significantly: Total fat (higher in Almond), CHO (lower in Almond), alpha-tocopherol and magnesium (higher in Almond) | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline, 4 wk, and 8 wk.; Group*Time effect; [underlined: TC], mg/dL; Almond vs Graham cracker: P=NS; [underlined: LDL], mg/dL; Almond vs Graham cracker: P=NS; [underlined: HDL], mg/dL; Almond vs Graham cracker: P<0.05 Decrease in HDL was smaller for Almond group vs Graham cracker group; [underlined: Triglycerides], mg/dL; Almond vs Graham cracker: P=NS; Analyses stratified by weight status and fasting glucose were also conducted. See Dhillon, 2018 for more details | Model adjustments:; Subject at random effect, study week as within-subject factor; Limitations:; - No information provided on randomization method; - No preregistered statistical analysis plan, analyzed outcome multiple ways; Funding sources:; Almond Board of California
Dias, 2017 (https://www.ncbi.nlm.nih.gov/pubmed/28488685) ^65^; RCT parallel, Australia; Baseline N=33 Analytic N=26 (Attrition: 21%); Participant characteristics at baseline: Healthy adults from 18 to 65 years without previous history of CVD and no differences in age, BMI, and blood lipids at baseline; Summary of findings:; Total blood, LDL, HDL cholesterol and triglycerides was not significantly different between those who consumed foods high in SFA (butter and white chocolate) and n-6 PUFA (margarine and sunflower seeds). | Intervention and comparator:; - SFA (n=14): daily consumption of 24 g butter, 40 g white chocolate (30 g fat, 20.9 g SFA); - n-6 PUFA (n=12): daily consumption of 20 g margarine, 42 g sunflower seeds (30 g fat, 20 g n-6 PUFA); [underlined: Duration of intervention:] 6 wk; [underlined: Compliance:] counting interventional food products provided; diet records; participants with low compliance (<80%) excluded from analysis; participants complied with study protocol based on plasma fatty acids; [underlined: Dietary intake for SFA vs n-6 PUFA:]; Total fat: NS between groups; SFA: Increased for SFA group, decreased for n-6 PUFA group (within-group: both P<0.01); LA: decreased for SFA group; increased for n-6 PUFA group (within-group: both P<0.01); Total PUFA: NR; Cholesterol: P=NS; Other components of diet differed significantly: NR | Outcomes and assessment methods:; Fasting blood lipids at baseline and 6wk; Difference in change; [underlined: TC], mmol/L, Median (IQR); SFA vs n-6 PUFA: NS; [underlined: LDL], mmol/L, Median (IQR); SFA vs n-6 PUFA: NS; [underlined: HDL], mmol/L, Median (IQR); SFA vs n-6 PUFA: NS; [underlined: Triglycerides], mmol/L, Median (IQR); SFA vs n-6 PUFA: NS | Model adjustments:; None; Limitations:; - Attrition >10%; - No preregistered statistical analysis plan; Funding sources:; Hunter Medical Research Institute; Faculty of Health, University of Newcastle, Australia
Egert, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/20521076) ^67^; RCT parallel, Germany; Baseline=47 Analytic N=37 (Attrition: 21%); Participant characteristics at baseline: Healthy technical school students, ~23 y, 68% female, BMI ~21.5; Summary of findings:; There was a significant between-group difference in change in total cholesterol among participants who consumed a high-MUFA, low-fat (~15%E MUFA) and a high-MUFA, high-fat (~20%E MUFA), over a 4 week period in young adults. No significant between-group differences were found in LDL- and HDL cholesterol and triglycerides. | Intervention and comparator:; - High-fat (40%E) MUFA-rich diet: 42.5g/day plant oils, 32.7g/day margarine (n=18); - ~10% SFA, 20%E MUFA, ~9% PUFA; - Low-fat (29%E) MUFA-rich diet: 25.7g/day plant oils, 24.1g/day margarine (n=19); - ~8% SFA, ~15%E MUFA, ~7% PUFA; - All meals provided by researchers. Intervention diets isocaloric, with consistent fatty acid content: SFA, MUFA, and PUFA (26%, 51% and 23% total fatty acids, respectively) and consistency in type of carbohydrate content.; - Principle source of fat: rapeseed oil and high-oleic sunflower oil and a MUFA-rich commercial margarine (MUFA, 48% of total fatty acids; 64 g fat/100 g) incorporated in sauces, desserts, curd and salad dressing; [underlined: Duration of intervention:] 4 wk (2 wk high-fat, high-SFA run-in diet); [underlined: Compliance:] Assessed via 3-day dietary records, reported to be high; no significant change in body weight; [underlined: Dietary composition of Low-fat vs High fat diets, Mean (SD):]; SFA (%E): 7.2 (0.2) vs 9.9 (0.4); MUFA (%E): 13.9 (0.4) vs 19.8 (0.3); PUFA (n-6) (%E): 5.3 (0.1) vs 7.0 (0.2); PUFA (n-3) (%E): 0.9 (0.0) vs 1.6 (0.1); Cholesterol (mg/MJ): 15.4 (0.9) vs 17.8 (0.9), P=NS; No significant difference in fiber and antioxidants. | Outcomes and assessment methods:; Fasting blood lipids: Prewash-in, after wash-in, after 2 wk and after 4 wk of the study diet.; Repeat measures with time (post wash-in, intervention diet wk 2 and wk 4) and group (high and low fat diet groups); [underlined: TC, mmol/L, Mean (SD)]; Baseline (after run-in), 4 wk levels; High-fat: 4.54 (0.75), 4.10 (0.68); Low-fat: 4.93 (0.66), 4.38 (0.77); Time*group interaction: P=0.037; [underlined: LDL, mmol/L]; High-fat vs low-fat: NS; [underlined: HDL, mmol/L]; High-fat vs low-fat: NS; [underlined: Triglycerides, mmol/L]; High-fat vs low-fat: NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - Attrition >10%; - No preregistered statistical analysis plan; Funding sources:; German Union for the Promotion of Oil- and Protein-containing Plants
Farajbakhsh, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/31089253) ^70^; RCT parallel, Iran; Baseline N=75 Analytic N=70 (Attrition: 7%); Participant characteristics at baseline: Adults (~64% female) ~49y of age with metabolic syndrome and who were (on average) with overweight or obesity.; Summary of findings:; In adults with metabolic syndrome, consumption of sesame oil for 8 weeks (which increased MUFA intake) resulted in greater improvements in total blood and HDL cholesterol and triglycerides compared to sunflower oil (which increased PUFA intake). | Intervention and comparators:; - Sesame Oil enriched with Vitamin E (Vit E) (400mg), 30mL/d (n=23); - SFA: 13%, MUFA: 43% (C18:1 43%), PUFA: 44%, LA: 42%, ALA: 1.2%; - Sesame Oil, 30mL/d (n=24); - SFA: 13%, [underlined: MUFA 44% (C18:1 43%)], PUFA: 44%, LA: 41%, ALA: 1.1%; - Sunflower Oil, 30mL/d (n=23); - SFA: 13%, MUFA: 31% (C18:1 31%), [underlined: PUFA: 56%], LA: 54%, ALA: 0.2%; - Participants instructed to add test oils to their salad, rice, or other food components. All participants received dietary recommendations to consume 55% CHO, 15% protein, and 30% fat; [underlined: Duration of intervention:] 8 wk (2 wk run-in); [underlined: Compliance:] Monitored via weekly phone call or in person; [underlined: Total dietary intake at 8 wk for Sesame Oil + Vit E vs Sesame Oil vs Sunflower Oil, Mean (SD), %E:]; SFA: 13.4 (0.1) vs 12.8 (0.7) vs 12.8 (0.7), P=NS; MUFA: 12.5 (0.8) vs 11.2 (0.2) vs 6.2 (0.2), P=0.02; PUFA: 5.7 (0.4) vs 5.1 (0.2) vs 12.1 (0.2), P=0.01; n-3 PUFA: 1.19 (0.4) vs 1.24 (0.3) vs 1.3 (0.2), P=NS; Cholesterol: NR; Other components of diet differed significantly: None | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline and at end of 8 wk.; Comparing change in blood lipids; [underlined: TC], mg/dL, Mean (SD), Baseline, 8wk, change; Sesame Oil + Vit E: 190.5 (34.7), 173.2 (32.1); −17.3; Sesame Oil: 190.7 (53.9), 177.2 (45.3); −13.5; Sunflower Oil: 186.8 (41.1), 189.8 (40.4); 3; P=0.005 (pairwise comparisons NR); [underlined: LDL], mg/dL; Sesame Oil + Vit E vs Sesame Oil vs Sunflower Oil: P=NS; [underlined: HDL], mg/dL, Mean (SD), Baseline, 8wk, change; Sesame Oil + Vit E: 34.8 (5.7), 36.8 (5.0); 4; Sesame Oil: 35.9 (7.2), 36.4 (6.2); 0.5; Sunflower Oil: 37.1 (8.4), 37.3 (7.6); 0.2; P=0.002 (pairwise comparisons NR); [underlined: Triglycerides], mg/dL Mean (SD); Baseline, 8wk, change; Sesame Oil + Vit E: 149.3 (35.1), 128.1 (30.8); −21.2; Sesame Oil: 170.9 (72.5), 157.7 (70.0); −13.2; Sunflower Oil: 138.7 (60.4), 147.6 (69.7); 8.9; P=0.001 (pairwise comparisons NR) | Model adjustments:; None; Limitations:; - No information provided on randomization method; - Information on compliance NR; - No preregistered statistical analysis plan; Funding sources:; Shiraz University of Medical Sciences
Gagliardi, 2010 (https://pubmed.ncbi.nlm.nih.gov/20648041) ^71^; RCT parallel, Brazil; Baseline N=75 Analytic N=53 (Attrition: 29%); Participant characteristics at baseline: Participants (62% women) aged ~54 years with metabolic syndrome. No differences in clinical and biochemical parameters between groups; Summary of findings:; Participants who consumed butter, compared to no-trans-fat margarine, did not have significant differences in total blood, LDL, HDL cholesterol, and triglycerides. | Intervention and comparator:; - Butter (n=18, 18 g/day): 67% SFA, 27% MUFA, 2% PUFA, 1% trans fat; - No-trans-fat margarine (n=16, 36 g/day): 25% SFA, 22% MUFA, 53% PUFA, 0.5% trans fat; [underlined: Duration of intervention:] 5 wk; [underlined: Compliance:] telephone calls; compliance defined as minimum consumption of at least 30 days supply of spread product provided and less than 3 days of consecutive non-consumption of the spread; [underlined: Dietary intake for Intervention vs Control at 5 wk, Mean (SD), g/day:]; SFA: 12.9 (5.8) vs 9.8 (4.1); MUFA: 10.6 (4.3) vs 9.0 (3.0); PUFA: 6.5 (2.5) vs 7.5 (4.2); Cholesterol (mg/day): 212 (98) vs 326 (230); Other components of diet differed significantly: NR | Outcomes and assessment methods:; Fasting blood lipids at 5 wk follow-up; Difference in change; [underlined: TC], mg/dL, Median (min, max); Butter vs No-trans-fat margarine: NS; [underlined: LDL], mg/dL, Median (min, max); Butter vs No-trans-fat margarine: NS; [underlined: HDL], mg/dL, Median (min, max); Butter vs No-trans-fat margarine: NS; [underlined: Triglycerides], mg/dL, Median (min, max); Butter vs No-trans-fat margarine: NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - Attrition >10%; - No preregistered statistical analysis plan; Funding sources:; National Research and Scientific Council, Fundacao de Amparo a Pesquisa do Estado de Sao Paulo, Proap; USDA; spread provided by Unilever Corporation and Laticinios Aviacao-Goncalves Salles SA
Grieger, 2014 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3895208/) ^73^; RCT parallel, Australia; Baseline N=83 Analytic N=80 (Attrition: 4%); Participant characteristics at baseline: Participants 64 years and older, BMI ~26, with slightly elevated blood lipids at baseline; Summary of findings:; Fish intake, compared to red meat intake, did not affect total blood cholesterol, LDL, HDL cholesterol or triglyceride levels. | Intervention and comparator:; - Fish (n=43): 8 servings of mixed fish per 2 weeks (~800 mg/day of EPA+DHA); total fat from food: 7.0 g/day; - Control (n=37): usual diet + 8 servings (68 g/day) of red meat per 2 weeks (~17 mg/day EPA; 4 mg/day DHA): total fat from food: 4.7 g/day; [underlined: Duration of intervention:] 8 wk; [underlined: Compliance:] participant interviews; 3-day weighed food records at wk 7; compliance met; [underlined: Dietary intake from study fish or study red meat for Intervention (Fish) vs Control at wk 7, Mean (SD):]; SFA (g): 2.6 (2.4) vs 3.4 (2.6); MUFA: NR; very long chain n-3 PUFA (mg/day): 1,399 (1,244) vs 80 (60); Cholesterol: NR; Other components of diet differed significantly: None; [underlined: Overall dietary intake for Intervention (Fish) vs Control at wk 7, Mean (SD), g/day unless noted:]; SFA: 28 (2) vs 28 (2), P=NS; MUFA: 30 (2) vs 24 (1), P<0.05; PUFA: 13 (1) vs 9(1), P<0.05; Cholesterol: 271 (17) vs 288 (26), P=NS; very long chain n-3 PUFA (mg): 1208 (156) vs 39 (6), P<0.01; EPA (mg): 446 (60) vs 11 (1), P<0.01; DPA (mg): 126 (19) vs 13 (2), P<0.01; DHA (mg): 636 (82) vs 15 (4), P<0.01; Other components of diet differed significantly: Zinc (greater in fish group), P<0.01 | Outcomes and assessment methods:; Fasting blood lipids at baseline and 8 wk follow-up; Levels at 8wk follow-up; [underlined: TC], mmol/L, Geometric Mean (SE); Fish vs control: NS; [underlined: LDL], mmol/L, Geometric Mean (SE); Fish vs control: NS; [underlined: HDL], mmol/L, Geometric Mean (SE); Fish vs control: NS; [underlined: Triglycerides], mmol/L, Geometric Mean (SE); Fish vs control: NS | Model adjustments:; None; Limitations:; - No information on randomization of allocation sequence; - No preregistered statistical analysis plan; Funding sources:; Australian Seafood Corporation Research Center
Hagen, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/27363518) ^74^; RCT parallel, Norway; Baseline N=45 Analytic N=38 (Attrition: 16%); Participant characteristics at baseline: Participants aged 20-35y with normal BMI <25; Summary of findings:; Participants who consumed fatty fish, compared to lean meat, had significantly higher HDL cholesterol and triglycerides but there was no difference in total or LDL cholesterol. Participants who consumed fatty fish, compared to lean fish, had significantly higher HDL cholesterol. There were no differences between lean fish vs lean meat consumers in total blood cholesterol, LDL or HDL, cholesterol or triglycerides. | Intervention and comparators:; - Lean fish (cod) (n=14): 750 g (5 meals of 150 g); - Fatty fish (salmon) (n=15): 750 g (5 meals of 150 g); - Lean meat (chicken) (n=16): 750 g (5 meals of 150 g); [underlined: Duration of intervention:] 4 wk; [underlined: Compliance:] participant interviews about intake; participants who did not comply with protocol were withdrawn from study; [underlined: Dietary intake for Lean fish, fatty fish, lean meat, respectively, Median (25^th^-75th), g/day:]; SFA (%E): 11 (9, 17), 14 (11, 16), 13 (10, 20), P=0.45; MUFA (%E): 11 (8, 16), 12 (10, 15), 13 (9, 17), P=0.21; PUFA: 5 (3, 9), 7 (5, 12), 6 (5, 9), P=0.55; Cholesterol: NR; Other components of diet differed significantly: None | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 wk follow-up; Difference in change; [underlined: TC], mmol/L, Median (25^th^-75^th^); Lean fish vs fatty fish vs lean meat: NS; [underlined: LDL], mmol/L, Median (25^th^-75^th^); Lean fish vs fatty fish vs lean meat: NS; [underlined: HDL], mmol/L, Median (25^th^-75^th^); Lean fish: 1.6 (1.4, 1.9); Fatty fish: 1.7 (1.4, 2.0); Lean meat: 1.4 (1.3, 2.1); Lean fish vs lean meat: NS; Fatty fish vs lean meat: P=0.025; Fatty fish vs lean fish: P=0.033; [underlined: Triglycerides], mmol/L, Median (25^th^-75^th^); Lean fish: 0.64 (0.43, 0.80); Fatty fish: 0.73 (0.55, 0.84); Lean meat: 0.66 (0.50, 1.26); Lean fish vs lean meat: NS; Fatty fish vs lean meat: P=0.018; Fatty fish vs lean fish: NS | Model adjustments:; None; Limitations:; - No information on randomization of allocation sequence; - Missing data was different between groups; - No preregistered statistical analysis plan; Funding sources:; Bergen Medical Research Foundation; KG Jebsen Center for Diabetes Research; fish and chicken from ICA Maxi;
Hallund, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/20594395) ^75^; RCT parallel, Denmark; Baseline N=75 Analytic N=68 (Attrition: 9%); Participant characteristics at baseline: Healthy male aged 40-70 y with no history of CVD or diabetes and similar BMI, energy intake, protein, carbohydrate and fiber intake at baseline; Summary of findings:; Consumption of farmed trout on marine feed, farmed trout on vegetable feed or chicken and rapeseed oil did not result in changes in total cholesterol, LDL, HDL cholesterol or triglycerides. | Intervention and comparators:; - Farmed trout on marine feed (150 g), daily meal, n=23; - Farmed trout on vegetable feed (150 g), daily meal, n=23; - Chicken (150 g) + 3.5 g rapeseed oil (to provide same amount of fat), daily meal, n=22; - Weekly meal plan provided by researchers; [underlined: Fatty acid composition of marine trout, vegetable trout and chicken (%):]; SFA: 25 (0.2) vs 15.2 (0.3) vs 20.8 (1.4); MUFA: 32.0 (1.0) vs 51.8 (1.0) vs 47.2 (1.8); PUFA: 35.7 (1.0) vs 30.3 (0.8) vs 32.1 (2.9); LA: 3.7 (0.1) vs 15.1 (0.2) vs 22.1 (1.7); AA: 0.7 (0.04) vs 0.8 (0.04) vs 1.8 (0.3); ALA: 1.2 (0.02) vs 3.5 (0.1) vs 3.2 (0.4); EPA: 6.9 (0.2) vs 1.3 (0.1) vs 0.3 (0.04); DHA: 16.3 (0.7) vs 5.1 (0.8) vs 0.5 (0.1); DPA: 2.6 (0.04) vs 0.5 (0.04) vs 0.8 (0.1); [underlined: Duration of intervention:] 8 wk; [underlined: Compliance:] study diaries; 99% compliant; [underlined: Dietary intake by intervention groups:] NR | Outcomes and assessment methods:; Fasting blood lipids at baseline and 8 wk follow-up; Levels at 8wk follow-up, mixed ANOVA; [underlined: TC], mmol/L, Mean (SEM); Marine trout vs vegetable trout vs chicken: NS; [underlined: LDL], mmol/L, Mean (SEM); Marine trout vs vegetable trout vs chicken: NS; [underlined: HDL], mmol/L, Mean (SEM); Marine trout vs vegetable trout vs chicken: NS; [underlined: Triglycerides], mmol/L, Mean (SEM); Marine trout vs vegetable trout vs chicken: NS | Model adjustments:; Baseline values; Limitations:; - No information on randomization of allocation sequence; - No preregistered statistical analysis plan; Funding sources:; Danish Council for Strategic Research
Iggman, 2014 (https://www.ncbi.nlm.nih.gov/pubmed/25319187) ^78^; RCT parallel, LIPOGAIN, Sweden; Baseline N=39 Analytic N=39 (Attrition: 0%); Participant characteristics at baseline: Healthy, predominantly White (90%) adults (31% female) ~27y of age without overweight or obesity; Summary of findings:; In healthy, young adults participating in an overfeeding trial, consumption of muffins high in n-6 PUFA from sunflower oil for 7 weeks (which increased PUFA intake) did not result in changes to blood lipids significantly different from changes in lipids from consumption of muffins high in SFA from palm oil (which increased SFA intake). | Intervention and comparator:; - Muffins high in n-6 PUFA (mainly LA) from refined sunflower oil, ~4, 240kcal muffins/d (n=19); - Muffins high in SFA from refined palm oil (mainly palmitic acid), ~4, 240kcal muffins/d (n=20); - Both interventions aimed to induce 3% weight gain by end of study; Number of muffins/d added to habitual diet modulated to control weight gain; - Each muffin contained 51%E fat; Types of fat in refined sunflower oil vs refined palm oil (%), previously reported:; SFA: 11% vs 54%; MUFA: 24% vs 37%; PUFA: 65% vs 9%; C16:0: 6% vs 48%; Oleic acid: 24% vs 37%; LA: 65% vs 9%; ALA: 0.08% vs 0.23%; [underlined: Duration of intervention:] 7 wk; [underlined: Compliance:] Monitored via weekly phone call or in person; “good compliance” with diets; [underlined: Change in dietary intake for PUFA muffin vs SFA muffin, Mean (SD), %E:]; SFA: −1.6 (2.8) vs 4.9 (2.8), P=0.0001; MUFA: 0.9 (2.7) vs 3 (2.7), P=0.026; PUFA: 7.9 (2.1) vs 0.3 (1.3), P=0.0001; n-3 PUFA: 1.19 (0.4) vs 1.24 (0.3) vs 1.3 (0.2), P=NS; Cholesterol: NR; Other components of diet differed significantly: None | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline and at end of 7 weeks.; Comparing between-group differences in change in blood lipids; [underlined: TC], mmol/L; PUFA muffin vs SFA muffin: P=NS; [underlined: LDL], mmol/L; PUFA muffin vs SFA muffin: P=NS; [underlined: HDL], mmol/L; PUFA muffin vs SFA muffin: P=NS; [underlined: Triglycerides], mmol/L; PUFA muffin vs SFA muffin: P=NS | Model adjustments:; None; Limitations:; - No preregistered statistical analysis plan; Funding sources:; Swedish Research Council; Swedish Society of Medicine; Lennanders Foundation; Uppsala-Orebro Regional Research Council
Jaakkola, 2017 (https://pubmed.ncbi.nlm.nih.gov/28727955/) ^81^; RCT parallel, Finland; Baseline N=2161 Analytic N=1204 (Attrition: 44%); Participant characteristics at baseline: 100% White parents of STRIP participants aged ~31y at baseline; Summary of findings:; Intervention mothers, compared to control mothers, had significantly lower total blood cholesterol and LDL cholesterol after a dietary counseling intervention targeting the participants’ child between ages 7mo to 20 years. These findings were not significant for fathers. There were no differences in HDL cholesterol and triglycerides between groups for mothers and fathers. | Intervention and comparator:; - Dietary counseling aimed to decrease saturated fat and increase unsaturated fat intake of the child; additionally, children were encouraged to consume more vegetables, fruits, berries, and whole-grain products and to lower salt intake; - Usual care; [underlined: Duration of intervention:] Child’s age at 7 months to 20 years; [underlined: Compliance]: 1-day food record recorded biennially between child’s age 9 to 19 years; [underlined: Dietary intake for Intervention vs Control, Mean (SE):]; SFA:; Mothers: 12.0 (0.18) vs 13.8 (0.16)%E, P<0.0001; Fathers: 12.3 (0.20) vs 13.9 (0.18)%E, P<0.0001; MUFA:; Mothers: 12.2 (0.15) vs 11.6 (0.14)%E, P=0.01; Fathers, 12.8 (0.19) vs 12.2 (0.16)%E, P=0.04; PUFA:; Mothers: 6.1 (0.08) vs 5.4 (0.07)%E, P<0.0001; Fathers: 6.4 (0.10) vs 5.8 (0.09)%E, P=0.0001; P/S ratio:; Mothers: 0.56 (0.01) vs 0.44 (0.01), P<0.0001; Fathers: 0.56 (0.01) vs 0.47 (0.01), P<0.0001; Other components that differed between groups: Protein intake was higher in intervention fathers compared to control fathers (18.1 vs 17.6%E, P=0.02) | Outcomes and assessment methods:; Fasting blood lipids: measured repeatedly during follow-up between child’s age 9-19 years; Levels at follow-up between the child’s ages of 9 to 19 years; [underlined: TC], mmol/L, Mean (SE); [underlined: Mothers:]; Intervention: 5.01 (0.04); Control: 5.14 (0.04); P=0.03; [underlined: Fathers:]; Intervention vs Control: NS; [underlined: HDL], mmol/L, Mean (SE); [underlined: Mothers:]; Intervention vs Control: NS; [underlined: Fathers:]; Intervention vs Control: NS; [underlined: LDL], mmol/L, Mean (SE); [underlined: Mothers:]; Intervention: 3.18 (0.04); Control: 3.30 (0.03); P=0.02; [underlined: Fathers:]; Intervention vs Control: NS; [underlined: Triglycerides], mmol/L, Mean (SE); [underlined: Mothers:]; Intervention vs Control: NS; [underlined: Fathers:]; Intervention vs Control: NS | Model adjustments:; Apo B cholesterol at baseline (for total cholesterol and LDL cholesterol for mothers); Limitations:; - No preregistered statistical analysis plan; Funding sources:; The Academy of Finland; Finnish Cardiac Research Foundation, Juho Vainio Foundation; Finnish Cultural Foundation; Sigrid Juselius Foundation; Yrjo Jahnsson Foundation
Jebb, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/20739418) ^82^; RCT parallel, RISCK trial, U.K.; Baseline=720 Analytic N=548 (Attrition: 24%); Participant characteristics at baseline: At risk for metabolic syndrome, ~52 y, 58% female, BMI ~28.5, 80% White, 80% central obesity, 25.5% low HDL, 72% high-TC, no CVD, no type 2 diabetes; Summary of findings:; A low fat diet or a high monounsaturated fat diet consumed for 24 weeks, compared to a high saturated fat diet, significantly decreased total and LDL cholesterol in adults at risk for metabolic syndrome. The low fat diet lowered HDL cholesterol significantly more than diets high in monounsaturated fat or high in saturated fat. No significant differences in triglyceride changes were observed between groups. | Intervention and comparators:; - High-SFA, high glycemic index (HS/HGI) (n=85); - High-MUFA and HGI (HM/HGI) (n=111); - HM and low glycemic index (HM/LGI) (n=116); - Low-fat and HGI (LF/HGI) (n=116); - LF and LGI (LF/LGI) diets (n=121); Analysis by fat type:; - High-SFA: Fat 38%E, CHO 45%E, SFA 16.6%E, MUFA 12%E (n=85); - High-MUFA: Fat 38%E, CHO 45%E, SFA 10%E, MUFA 20%E (n=227); - Low-fat: Fat 28%E, CHO 55%E, SFA 10%E, MUFA 12%E (n=236); - Isocaloric diets, key sources of fat (i.e., spreads, cooking oils, and margarine) and carbohydrates (i.e., bread, pasta, rice, and cereals) provided by researchers with additional dietary information tailored to the study group; [underlined: Duration of intervention:] 24 wk (4 wk run-in on HS/HGI diet); [underlined: Compliance]: Assessed via food diaries; small decrease in weight with LF diet (~1kg); GI was ~8 GI points lower in LGI diets than the HGI diets compared to the target of 11–13 GI points.; [underlined: Change in energy source from HS/HGI diet (ref), Mean (95% CI), HS/HGI vs HM/LGI vs LF/HGI vs LF/LGI]; [underlined: HS/HGI Mean (SD) (ref) (%E): SFA: 16.5 (3.0), MUFA: 11.6 (2.1), PUFA: 5.8 (1.7), CHO: 43.0 (6.5)]; SFA (%E): −0.5 (−1.5, 0.6)a vs −7.0 (−7.9, −6.0)b vs −6.9 (−7.8, −6.0)b vs −7.3 (−8.3, −6.4)b,c vs −8.2 (−9.1, −7.3)c, a vs b vs c P<0.05; MUFA (%E): −0.1 (−1.2, 1.0)a vs 4.6 (3.6, 5.6)b vs 4.7 (3.7, 5.6)b vs −1.8 (−2.8, −0.8)c vs −1.9 (−2.8, −1.0)c, a vs b vs c P<0.05; PUFA (%E): 0.0 (−0.7, 0.7)a,c vs 0.8 (0.2, 1.4)a,b vs 1.1 (0.5, 1.7)b vs −0.6 (−1.2, 0.0)c vs −0.7 (−1.4, −0.2)c, a vs b vs c P<0.05; CHO (%E): −1.0 (−3.1, 1.0)a vs 1.9 (0.1, 3.7)b vs 1.6 (−0.2, 3.4)b vs 8.1 (6.3, 9.9)c vs 8.5 (6.8, 10.2)c, a vs b vs c P<0.05; Glycemic index: 0.5 (−0.7, 1.8)a vs −0.2 (−1.3, 1.0)a vs −8.3 (−9.4, −7.2)b vs 0.9 (−0.3, 2.0)a vs −7.2 (−8.3, −6.1)b, a vs b vs c P<0.05 | Outcomes and assessment methods:; Fasting blood lipids: At baseline and following the feeding period.; [underlined: TC], mmol/L, % Change from baseline.; Mean (95% CI):; HS/HGI: −1.2 (−3.1, 0.6); HM/HGI: −3.9 (−5.7, −2.1); HM/LGI: −7.0 (−8.9, −5.0); LF/HGI: −5.7 (−7.4, −4.0); LF/LGI: −6.7 (−8.5, −4.8); Between groups P=0.0006; HS/HGI vs HM/HGI, HM/LGI, LF/HGI, LF/LGI: P<0.001 (lower TC in comparator than HS/HGI); High SFA vs High MUFA: P=0.001; High SFA vs Low-fat: P=0.001; High MUFA vs Low-fat: NS; [underlined: LDL], mmol/L, % Change from baseline, Mean (95% CI):; HS/HGI: −0.6 (−3.4, 2.1); HM/HGI: −5.2 (−7.8, −2.6); HM/LGI: −7.8 (−10.2, −5.5); LF/HGI: −7.0 (−9.2, −4.8); LF/LGI: −7.0 (−9.5, −4.5); Between groups: P=0.0015; HS/HGI vs HM/HGI, HM/LGI, LF/HGI, LF/LGI: P<0.001 (lower LDL in comparator than HS/HGI); High SFA vs High MUFA: P=0.001; High SFA vs Low-fat: P=0.001; High MUFA vs Low-fat: NS; [underlined: HDL], mmol/L, % Change from baseline, Mean (95% CI); HS/HGI: −2.0 (−4.3, 0.3); HM/HGI: −2.7 (−4.6, −0.9); HM/LGI: −4.3 (−6.3, −2.2); LF/HGI: −5.9 (−7.7, −4.0); LF/LGI: −7.2 (−8.9, −5.5); Between groups: P=0.0009; High SFA vs High MUFA: NS; High SFA vs Low-fat: P=0.001; High MUFA vs Low-fat: P=0.002; [underlined: Triglycerides], mmol/L, %Change from baseline, Mean (95% CI):; Between groups: NS | Model adjustments:; Center, ethnicity, baseline waist, baseline age, baseline HDL cholesterol, sex, and diet, weight change; Limitations:; - Attrition >10%; - Study preregistration could not be located; Funding sources:; U.K. Food Standards Agency
Kalgaonkar, 2011 (https://www.ncbi.nlm.nih.gov/pubmed/21157477) ^84^; RCT parallel, U.S.; Baseline N=36 Analytic N=31 (Attrition: 14%); Participant characteristics at baseline: Women ~33y of age (predominantly white) with PCOS and with overweight or obesity.; Summary of findings:; In women with PCOS, consumption of walnuts for 6 weeks (which increased LA and ALA intake) did not significantly change blood lipids compared to consumption of almonds. | Intervention and comparator:; - Walnuts, 36g/day/1800kcal daily (n=17); - Sources: walnuts; - Almonds, 46g/day/1800kcal (n=14); - Sources: almonds; - Both groups replaced 31 g/day dietary fat/1800kcal with nuts; counseled by study dietitian to maintain fat and energy intake constant; [underlined: Duration of intervention:] 6 wk; [underlined: Compliance:] Assessed via return of unused portions of nuts; Participants consumed all the nuts.; [underlined: Dietary intake at 6 wk for Walnuts vs Almonds, Mean (SE), g/d, Comparing change between groups:]; SFA: 32 (3) vs 29 (5), P=NS; MUFA: 19 (3) vs 35 (3), P=NS; LA: 15.0 (1.0) vs 7.5 (0.6), P=0.0163; ALA: 3.25 (0.3) vs 0.34 (0.07), P=0.0002; Cholesterol (mg/d): 167 (30) vs 225 (26), P=NS; Other components of diet differed significantly: None | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline and 4 wk; Comparing change from baseline between groups; [underlined: TC], mmol/L; Walnut vs Almond: P=NS; [underlined: LDL], mmol/L; Walnut vs Almond: P=NS; [underlined: HDL], mmol/L; Walnut vs Almond: P=NS; [underlined: Triglycerides], mmol/L; Walnut vs Almond: P=NS | Model adjustments:; Baseline blood lipid; Limitations:; - No information on randomization of allocation sequence; - Differential loss to follow-up with no information on whether results were robust to missing data; - No preregistered statistical analysis plan; Funding sources:; National Center for Complementary and Alternative Medicine; ALSAM Foundation; UC Davis Clinical and Translational Science Center
Khaw, 2018 (https://pubmed.ncbi.nlm.nih.gov/29511019) ^88^; RCT parallel, U.K.; Baseline N=96 Analytic N=91 (Attrition: 5%); Participant characteristics at baseline: Participants (~67% women) aged 50-75 years, 98% European Caucasian with no history of cancer, CVD or diabetes; Summary of findings:; Total cholesterol significantly increased in the butter group compared to the olive oil group. LDL cholesterol significantly increased in the butter group compared to the coconut oil and olive oil groups. HDL cholesterol significantly decreased in the butter group compared to the coconut oil group and significantly increased in the coconut oil vs olive oil group. | Intervention and comparators:; - Extra Virgin Coconut Oil (50 g/day), n=28; - 94% SFA: 48% lauric acid (C12:0), 19% myristic acid (C14:0), 9% palmitic acid (C16:0); 5% MUFA; 1% PUFA; - Butter (50 g/day), n=33; - 66% saturated fat: 40% palmitic acid (C16:0) and stearic (C18:0); 26% MUFA; 3% PUFA (2% LA and 1% ALA); 4% trans-fat; - Extra Virgin Olive Oil (50 g/day), n=30; - 19% SFA, 68% MUFA (oleic acid), 13% PUFA (LA); 14% PUFA; - Instructed to add test oils to usual diet; [underlined: Duration of intervention:] 4 wk; [underlined: Compliance:] online 24-hour DietWebQ, defined as >75% adherence; [underlined: Dietary intake for intervention groups:] NR | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 wk follow-up; [underlined: TC], mmol/L, Mean (SD), Difference; Butter vs coconut oil: NS; Butter vs olive oil: 0.38 (0.11, 0.64) (increased in butter); Coconut oil vs olive oil: NS; [underlined: LDL], mmol/L, Mean (SD), Difference; Butter vs coconut oil: 0.45 (0.22, 0.68), P<0.0001 (increased in butter); Butter vs olive oil: 0.40 (0.17, 0.62), P<0.0001 (increased in butter); Coconut oil vs olive oil: NS; [underlined: HDL], mmol/L, Mean (SD), Difference; Butter vs coconut oil: −0.19 (−0.31, −0.06) (increased in coconut oil); Butter vs olive oil: NS; Coconut oil vs olive oil: 0.17 (0.04, 0.29) (increased in coconut oil); [underlined: Triglycerides], mmol/L, Mean (SD), difference; Butter vs coconut oil: NS; Butter vs olive oil: NS; Coconut oil vs olive oil: NS | Model adjustments:; Age, sex, BMI at baseline; Limitations:; - No preregistered statistical analysis plan; Funding sources:; Broadcasting Corporation; University of Cambridge
Klempel, 2013 (https://www.ncbi.nlm.nih.gov/pubmed/23612508) ^89^; RCT parallel, U.S.; Baseline N=35, Analytic N=32 (Attrition: 9%); Participant characteristics at baseline: Females ~43y of age with obesity with no history of cardiovascular disease; Summary of findings:; In ~ 43y old women with obesity participating in a weight loss trial with alternate day fasting, intake of a high fat diet for 8 weeks did not significantly, change blood lipids compared to intake of a low fat diet. | Intervention and comparator:; - High Fat: 45% energy from total fat (14% SFA, 20% MUFA, 11% PUFA), n=15; - Low Fat: 25% energy from total fat (6% SFA, 13% MUFA, 6% PUFA), n=17; - Both groups put on weight loss diet and practiced alternate day fasting (25% energy on fast days, 125% energy on feed days).; - All meals provided by study; [underlined: Duration of intervention:] 10 wk (2 wk weight maintenance, 8 wk weight loss); [underlined: Compliance:] NR; [underlined: Diet composition for High Fat vs Low Fat, %E:]; SFA: 14% vs 6%; MUFA: 20% vs 13%; PUFA: 11% vs 6%; Cholesterol: NR; Other components of diet differed significantly: Carbohydrates (40% vs 60%) | Outcomes and assessment methods:; Fasting blood lipids: Assessed at study weeks 1, 3, and 10, measured in duplicate; Comparing % change; [underlined: TC], mg/dL; High fat vs Low fat: P=NS; [underlined: LDL], mg/dL; High fat vs Low fat: P=NS; [underlined: HDL], mg/dL; High fat vs Low fat: P=NS; [underlined: Triglycerides], mg/dL; High fat vs Low fat: P=NS | Model adjustments:; Time by treatment interaction; Limitations:; - Energy restricted diet; - No information on randomization of allocation sequence; - No preregistered statistical analysis plan; Funding sources:; Departmental grant, Kinesiology and Nutrition, University of Illinois, Chicago
Kruse, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/25403327) ^92^; RCT parallel, Germany; Baseline N=18 Analytic N=18 (Attrition: 0%); Participant characteristics at baseline: 100% overweight or obese men aged ~55 years with BMI ~29; Summary of findings:; Consumption of 50 g/day of rapeseed/canola oil, compared to cold-pressed extra virgin olive oil, did not result in significant differences between groups in total blood, LDL- and HDL-cholesterol, and triglycerides among overweight adults. | Intervention and comparator:; - Refined rapeseed/canola oil (RA) (50 g/day); higher in PUFA, especially ALA and n-6 LA; not to be used for baking or frying; - Types of fat in oil: NR; - Cold-pressed extra virgin olive oil (OL) (50 g/day); not to be used for baking or frying; - Types of fat in oil: NR; [underlined: Duration of intervention:] 4 wk; [underlined: Compliance:] 3-day food record at baseline and after 2^nd^ week of intervention; [underlined: Dietary intake for Intervention vs Control:] NR | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 wk follow-up; Comparing change from baseline; [underlined: TC], mmol/L; OL vs RA: NS; [underlined: LDL], mmol/L; OL vs RA: NS; [underlined: HDL], mmol/L; OL vs RA: NS; [underlined: Triglycerides], mmol/L; OL vs RA: NS | Model adjustments:; None; Limitations:; - No preregistered statistical analysis plan; Funding sources:; Union zur Forderung von Oel-und Proteinpflanzen e. V., Germany; German Institute of Human Nutrition, Potsdam-Rehbruecke
Lim, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/19692216) ^93^; RCT parallel, Australia; Baseline N=113 Analytic N=69 (Attrition: 49%); Participant characteristics at baseline: Participants (80% female) ~47 years who were overweight or obese with at least 1 CVD risk factor, no CVD, no diabetes; Summary of findings:; After 15mo, intervention groups vs control had improved total cholesterol, LDL cholesterol, SBP, and DBP. However, there were no significant differences between intervention groups. | Intervention and comparators:; - Very Low Carbohydrate (VLC) diet: 35%E PRO, 60%E FAT, 20%E SFA, 4%E CHO; - Very Low Fat (VLF) diet: 20%E PRO, 10%E FAT, 3%E SFA, 70%E CHO; - High Unsaturated Fat (HUF) diet: 20%E PRO, 30%E FAT, 6%E SFA, 8%E PUFA, 50% CHO; - Control: No dietary intervention received, intake NR; - All diets (except control) were energy-restricted and isocaloric with one another; [underlined: Duration of intervention:] 15mo (3 mo of intensive support followed by 12 mo of minimal support); [underlined: Compliance]: measured at 3, 6, 9, 12, and 15mo; lower compliance after 3 months; [underlined: Dietary intake for VLC vs VLF vs HUF at 3mo,/15mo, Mean (SD), %E:]; SFA: 17.7 (1.01)/13.2 (0.8), 5.1 (0.30)/10.7 (0.8), 6.0 (0.32)/9.9 (0.9); MUFA: 26.2 (1.41)/15.1 (1.4), 3.6 (0.21)/10.5 (0.9), 12.3 (0.51)/11.5 (0.6); PUFA: 6.5 (0.28)/5.5 (0.5), 1.8 (0.16)/4.3 (0.5), 7.2 (0.30)/5.6 (0.7); Cholesterol: 782.7 (24.7)/404.1 (58.1), 123.9 (5.4)/246.4 (31.4), 163.2 (17.2)/273.0 (33.1); Other components of diet differed significantly:; CHO (%E): 12.4 (3.38)/36.5 (2.9), 66.0 (0.92)/50.5 (1.8), 48.7 (1.07)/43.2 (2.7); PRO (%E): 30.5 (0.91)/23.9 (1.5), 20.3 (0.55)/19.6 (0.9), 21.4 (0.51)/24.4 (1.66); FAT (%E): 54.3 (2.53)/37.1 (2.4), 12.5 (0.59)/28.3 (1.8), 28.0 (0.88)/30.3 (1.7) | Outcomes and assessment methods:; Fasting blood lipids,: Measured at baseline, 3mo, 15mo; Changes from baseline to 3mo (VLC, VLF, HUF), 15mo (VLC, VLF, HUF, control), different letters significantly different; [underlined: TC], mmol/L, Mean (SD); 3mo: NS differences between groups; 15mo: Control: 0.5 (0.8) vs VLC: −0.4 (0.8), P<0.05 vs VLF: −0.3 (0.8), P<0.05 vs HUF: −0.3 (1.2), P<0.05; P=0.042; NS between VLC, VLF, vs HUF; [underlined: HDL], mmol/L, Mean (SD); 3mo: Control: 0.1 (0.2) (NS); VLC: 0.1 (0.2) vs VLF: −0.1 (0.2), P<0.05 vs HUF: −0.1 (0.2), P=0.025; NS between VLF vs HUF and between control vs all groups; 15mo: NS differences between groups; [underlined: LDL], mmol/L, Mean (SD); 3mo: VLC: 0.3 (1.0) vs VLF: −0.4 (0.6), P<0.05 vs HUF: −0.6 (1.1), P<0.05 vs control: 0.4 (0.7), P<0.05; P=0.015; NS between VLF, HUF vs control; 15mo: −0.3 (0.7)a, −0.3 (0.7)a, −0.1 (1.1)a, 0.4 (0.7)b, p=0.022; [underlined: Triglycerides], mmol/L, Mean (SD); 3mo: −0.7 (0.6)a, −0.1 (0.6)b, −0.2 (0.5)b, p=0.001; 15mo: NS differences between groups | Model adjustments:; None; Limitations:; - Weight loss trial; - No description of the randomization process and baseline imbalances in TC, and BP; - Potential bias due to missing data; - No preregistered statistical analysis plan; Funding sources:; National Heart Foundation, Australia and CSIRO Health Sciences and Nutrition
Lucci, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/26488229) ^95^; RCT parallel, Colombia; Baseline N=160 Analytic N=145 (Attrition: 9%); Participant characteristics at baseline: Participants aged 50 years or older, mean BMI ~28, without prior CVD; normal to high LDL cholesterol, total cholesterol and triglycerides values at baseline; baseline blood lipid values did not differ between groups at baseline; Summary of findings:; Consumption of extra virgin olive oil, compared to hybrid palm oil-rich diet, did not result in significant between-group differences in changes in total blood, LDL, and HDL cholesterol or triglycerides at 3 months. | Intervention and comparator:; - HPO: Hybrid palm oil-rich diet (25 mL/day, n=78); - EVOO: Rich extra-virgin olive oil diet (25 mL/day, n=82); [underlined: Types of fat in HPO vs EVOO (Mean, SD) %:]; SFA: 30.8 (1.6) vs 15.4 (0.8); MUFA: 56.1 (1.0) vs 77.2 (1.2); PUFA: 11.1 (0.7) vs 6.1 (0.4); C16:0: 27.9 (1.2) vs 12.5 (0.8); Oleic acid: 55.2 (1.3) vs 76.0 (1.2); LA: 10.8 (0.5) vs 5.5 (0.8); ALA: 0.4 (0.0) vs 0.6 (0.1); [underlined: Duration of intervention:] 3 months; [underlined: Compliance:] 24-hour food recall and FFQ at baseline and each follow-up visit (3); [underlined: Dietary intake for Intervention vs Control:] NR | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4, 8, and 12 wk follow-up; Repeated measures ANOVA; [underlined: TC], mg/dL; EVOO vs HPO: NS; [underlined: LDL], mg/dL; EVOO vs HPO: NS; [underlined: HDL], mg/dL; EVOO vs HPO: NS; [underlined: Triglycerides], mg/dL; EVOO vs HPO: NS | Model adjustments:; None; Limitations:; - No information on compliance; - No preregistered statistical analysis plan; Funding sources:; Pontificia Universidad Javeriana and Hacienda la Cabana donated oil samples
Lv, 2018 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6052506/) ^96^; RCT parallel, China; Baseline N=93 Analytic N=88 (Attrition: 5%); Participant characteristics at baseline: Participants aged ~21 with BMI ~21 with no history of CVD, HTN, diabetes or cancer; Summary of findings:; LDL cholesterol was significantly different between cocoa butter, palm olein, and soybean oil diets (which groups differed was NR). HDL cholesterol and triglycerides did not significantly differ between cocoa butter, palm olein and soybean oil diets | Intervention and comparator:; - Palm olein (n=28): 30-36 g/day; 46% SFA, [underlined: 44% MUFA], 10% PUFA, C16:0 29%, C18:0 3%, C18:1 50%, C18:2 15%, C18:3 0.3%; - Soybean oil (n=29): 30-36 g/day; 23% SFA, 28% MUFA, [underlined: 49% PUFA], C16:0 11%, C18:0 4%, C18:1 22%, [underlined: C18:2 52%], C18:3 6.7%; - Cocoa butter (n=31): 30-36 g/day; [underlined: 94% SFA], 6% MUFA, 0.4% PUFA, C16:0 26%, C18:0 37%, C18:1 36%, C18:2 2%, C18:3 0%; - SFA ratio of cocoa butter, palm olein, soybean oil: 4:2:1; - 5 days/wk all food provided by researchers; for weekend days, dietary advice was given on what foods to consume. Macronutrient and caloric compositions of test diets were identical.; - Oil used for staple food (walnut cake, ujube cake, or Cantonese sponge cake) was partially replaced with cocoa butter and palm olein.; [underlined: Duration of intervention:] 16 wk; [underlined: Compliance:] weighed food after intake; [underlined: Dietary intake for Intervention vs Control:] % energy of lipids were similar between groups | Outcomes and assessment methods:; Fasting blood lipids at baseline and wk follow-up; Repeated ANOVA; [underlined: LDL], mmol/L, Mean (SE); Levels at 16 wk:; Cocoa butter: 2.21 (0.10); Palm olein: 2.24 (0.11); Soybean oil: 2.00 (0.08); Cocoa butter vs palm olein vs soybean oil: P=0.031; [underlined: HDL], mmol/L, Mean (SE); Cocoa butter vs palm olein vs soybean oil: NS; [underlined: Triglycerides], mmol/L, Mean (SE); Cocoa butter vs palm olein vs soybean oil: NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - No preregistered statistical analysis plan; Funding sources:; Mutual fund of the Chinese Nutrition Society and Malaysian palm bureau; Capital Medical University provided diets
Michielsen, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/30725537) ^99^; RCT parallel, Netherlands; Baseline N=60 Analytic N=47 (Attrition: 22%); Participant characteristics at baseline: Healthy adults (57% female), ~55 y, BMI~27, at risk for metabolic syndrome, TC<8mmol/L, no drug treatment for dyslipidemia or HTN, no diabetes; Summary of findings:; None of the 3 test diets, 1) SFA-rich Western diet versus 2) MUFA rich diet (western type diet with SFA replaced by MUFA from olive oil) versus 3) Mediterranean diet (similar MUFA content) consumed for 8 weeks resulted in significant differences between groups in changes to total, LDL and HDL cholesterol among middle-aged adults at risk for metabolic syndrome. However, triglyceride levels decreased significantly more for the Mediterranean diet, compared to the SFA diet. | Intervention and comparator:; - SFA-rich diet (n=16) Western-type diet; - MUFA-rich diet (n=17) Western-type diet with part of SFA replaced by MUFA from olive oil (MUFA 20%E); - Mediterranean (MED) diet (n=14) similar MUFA content (21%E); - Med diet higher in fatty fish, legumes, nuts, unrefined grain products, and red wine, and lower in dairy products and meat, compared with the other two intervention diets; - Diets isocaloric; 90% of calories provided by study personnel; - Types of fat in diets NR; [underlined: Duration of intervention:] 8 wk (2 wk run-in on Western diet); [underlined: Compliance]: assessed via a food diary but NR; [underlined: Dietary intake for SFA vs MUFA vs Med Diet:] NR | Outcomes and assessment methods:; Fasting blood lipids assessed at baseline (after run-in) and after the 8 wk intervention; Change in lipid values from baseline; [underlined: TC], mmol/l, Mean (SD), False discovery rate p-value (FDRp); Between-group: FDRp=NS; [underlined: LDL], mmol/l, Mean (SD), FDRp; Between-group: FDRp=NS; [underlined: HDL], mmol/l, Mean (SD), FDRp; Between-group: FDRp=NS; [underlined: Triglycerides,] mmol/l, Mean (SD) FDRp; SFA diet: +0.069 (0.222); MUFA diet: −0.111 (0.271); Med diet: −0.257 (0.354); Between-group: FDRp=0.037; SFA vs MUFA: NS; SFA vs Med: P<0.05 | Model adjustments:; None; Limitations:; - No information provided on randomization method; - Potential deviation from intended intervention since compliance is not reported; - Registered protocol does not describe statistical analysis plan; Funding sources:; BioNH under Joint Programming Initiative; BBMRI-NL by Dutch government
Miller, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/27578132) ^100^; RCT parallel, Muffin Study, U.S.; Baseline N=39 Analytic N=34 (Attrition: 13%); Participant characteristics at baseline: Middle-aged adults ~60.8 y with metabolic syndrome, 79% African-American, 60% women; Summary of findings:; Diets that replaced SFA with PUFA versus MUFA over a 6 month period resulted in greater reductions in serum triglyceride levels and had no significant differential effect on blood total-, LDL- and HDL cholesterol in obese, middle-aged adults with metabolic syndrome following an AHA-type I diet to lose weight. | Intervention and comparator:; - MUFA (~12 grams high-oleic sunflower oil 3x/day) 10.3 g MUFA, 0.7 g PUFA, and 1.4 g SFA (n=15); - PUFA (~12 grams safflower oil 3x/day) 2 g MUFA, 9.2 g PUFA, 1 g SFA (n=19); - All participants were following the AHA Step I hypocaloric diet (45%–50% carbohydrates, 15%–20% protein and 30%–35% of fat, reduced energy ~300 kcal/d).; - Daily SFA intake reduced from 25-50% and replaced with either MUFA or PUFA; - Participants consumed 3 MUFA- or PUFA-enriched muffins/day; [underlined: Duration of intervention:] 6 months (1-2 month run-in on AHA Step 1 diet); [underlined: Compliance]: Compliance NR; assessed by 7-day food records; [underlined: Dietary intake for MUFA vs PUFA at 6 months, Mean (SD), %E:]; Total SFA: NS; Total MUFA: NR; Total PUFA: NR; C18:1 (Oleic acid, g): 24.8 (1.8) vs 13.1 (1.5), P<0.001; C18:2 (LA, g): 9.6 (0.9) vs 16.9 (1.2), P<0.001; C20:5 (EPA): NS; C22:6 (DHA): NS; MUFA/SFA (%): 167 (10) vs 104 (6); P=0.01; PUFA/SFA (%): 67 (5) vs 132 (11); P<0.0005; No significant between-group differences in total; Energy, CHO, protein, total fat intake over the 6 mo intervention. | Outcomes and assessment methods:; Fasting blood lipids: assessed at baseline and at 6 months; Change in lipid values from baseline; [underlined: TC], mg/dL, Mean (SE); MUFA vs PUFA: P=0.48; [underlined: LDL], mg/dL, Mean (SE); MUFA vs PUFA: P=0.92; [underlined: HDL], mg/dL, Mean (SE); MUFA vs PUFA: P=0.85; [underlined: Triglycerides], mg/dL, Mean (SE); MUFA: +6 (5); PUFA: −30 (18); MUFA vs PUFA: P=0.01 | Model adjustments:; Baseline value of the outcome measure, change in weight; Limitations:; - No information provided on randomization method; - Potential missing data bias due to not statistically accounting for missing data; - No preregistered statistical analysis plan; Funding sources:; VA Merit Grant Award; NHLBI
Ng, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/30126103) ^104^; RCT parallel, Malaysia; Baseline N=85 Analytic N=85 (Attrition: 0%); Participant characteristics at baseline: Overweight participants (~75% women) ~35 years, BMI ~26; Summary of findings:; Consumption of stearic acid, compared to palmitic oils, resulted in significantly reduced triglycerides. There were no significant differences in total blood, LDL, and HDL cholesterol between groups. | Intervention and comparator:; - Chemically-interesterified (CIE) oils baked into two test cupcakes and five pieces of test cookies with:; - IEPalm (n=29): Palmitic acid: C16:0 35%, C18:0 5%, C18:3 0.13% (refined, bleached and deodorized palm olein) ~20%E; - IEStear (n=28): Stearic acid: C16:0 8%, C18:0 39%, C18:3 0.04% (fully hydrogenated soybean oil, high oleic acid sunflower oil and sunflower oil) ~20%E; - NatPO (n=28): Natural palm olein: C16:0 38%, C18:0 4%, C18:3 0.23%; ~20%E; - Three test fats used to prepare daily snacks with a standard palm-based background diet. 5 days/wk meals provided by researchers.; [underlined: Duration of intervention:] 8 wk (3 wk run-in); [underlined: Compliance:] daily attendance list to record collection of test snacks and meal packs; [underlined: Dietary intake for IEPalm, IEStear and NatPO snacks, Mean (SD), kcal/day:]; SFA: 209.5 (2.0); 232.3 (3.2); 213.3 (19.6); MUFA: 221.6 (0.1); 200.3 (2.3); 215.1 (14.2); PUFA: 63.2 (2.0); 53.4 (1.2); 60.6 (5.4); Cholesterol: NR; Other components of diet differed significantly: None (energy of SFA, MUFA, PUFA of background diets were similar) | Outcomes and assessment methods:; Fasting blood lipids at baseline and 6, and 8 wk follow-up; Comparisons of between-group differences at 8 wk follow-up; [underlined: TC], mmol/L, Mean (SD); Palmitic vs Stearic vs Natural palm olein: NS; [underlined: LDL], mmol/L, Mean (SD); Palmitic vs Stearic vs Natural palm olein: NS; [underlined: HDL], mmol/L, Mean (SD); Palmitic vs Stearic vs Natural palm olein: NS; [underlined: Triglycerides], mmol/L, Mean (SD); Palmitic: 1.36 (0.69); Stearic: 1.16 (0.80); Natural palm olein: 1.39 (0.87); Palmitic vs Stearic: P=0.007; Palmitic vs Natural palm olein: NS; Stearic vs Natural palm olein: NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - No preregistered statistical analysis plan; Funding sources:; Malaysian Palm Oil Board
Ooi, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22773687) ^106^; RCT parallel, U.S.; Baseline N=NR Analytic N=20 (Attrition: NR); Participant characteristics at baseline: Participants ~66 years with BMI between 23-28 who had mild to moderate hypercholesterolemia at baseline; differences in blood lipid levels were observed at baseline; Summary of findings:; High-fish diet, compared to low-fish diet, significantly decreased triglycerides and resulted in a smaller decrease in HDL cholesterol levels after 24 weeks. There was no significant difference between the two diets on total and LDL cholesterol after 24 weeks. | Intervention and comparator:; - High-fish diet (n=10): EPA+DHA 1.23 g/day, SFA:4.5%E (SD=0.7); - Sources: Sole fillet, salmon, tuna; - Low-fish diet (n=10): EPA+DHA 0.27 g/day, SFA: 4.0%E (SD=0.4); - Sources: poultry; - All meals/snacks provided by researchers; [underlined: Duration of intervention:] 24 wk; [underlined: Compliance:] NR; [underlined: Dietary intake for Intervention vs Control:] NR | Outcomes and assessment methods:; Fasting blood lipids at baseline and 24 wk follow-up; [underlined: TC], mmol/L, Median (IQR); High-fish vs low-fish: NS; [underlined: LDL], mmol/L, Median (IQR); High-fish vs low-fish: NS; [underlined: HDL], mmol/L, Median (IQR); Levels at 24 wk; High-fish: 1.04 (0.71, 1.52); Low-fish: 0.93 (0.71, 1.21); Median % change from baseline diet; High-fish: −9; Low-fish: −19; Between-group difference: P=0.04; [underlined: Triglycerides], mmol/L, Median (IQR); Levels at 24wk; High-fish: 1.46 (1.21, 1.79); Low-fish: 1.76 (1.30, 2.07); Median % change from baseline diet; High-fish: −24; Low-fish: −1; Between-group difference: P=0.02 | Model adjustments:; None; Limitations:; - Potential problem in randomization process due to baseline imbalances; - No information on compliance; - No preregistered statistical analysis plan; Funding sources:; NIH; USDA; National Health and Medical Research Council
Raziani, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/27557654) ^110^; RCT parallel, Denmark; Baseline N=164 Analytic N=139 (Attrition: 15%); Participant characteristics at baseline: Adults (~66% female) ~53y of age at baseline, with BMI ~29, a high waist circumference and at least one additional risk factor for metabolic syndrome.; Summary of findings:; Consuming regular fat cheese (higher in SFA) for 12 weeks did not significantly change blood lipids compared to reduced fat cheese (lower in SFA) or a carbohydrate control. | Intervention and comparator diets:; - Regular fat cheese (REG), n=45; - Sources: Riberhus and Sharp Cheddar Cheese; - Reduced fat cheese (RED), n=48; - Sources: Reduced fat Riberhus and Sharp Cheddar Cheese; - Carbohydrate control (CHO), n=46; - Sources: White bread and jam; [underlined: Duration of intervention:] 12 wk (preceded by 2 wk run in); [underlined: Compliance:] Assessed via food diaries; >95% adherence to assigned intervention foods; [underlined: Total dietary intake for Regular fat cheese vs Reduced fat cheese vs Carbohydrate control, Mean (SD), g/d:]; SFA: 34.3 (2.3) vs 27.4 (1.2) vs 19.1 (1.4); REG vs RED P<0.01, REG vs CHO, P<0.001; MUFA: 30.1 (2.1) vs 27.1 (1.6) vs 23.9 (1.6); REG vs RED P=0.10, REG vs CHO P<0.01; PUFA: 13.7 (1.0) vs 13.0 (0.8) vs 13.3 (0.9); REG vs RED P=0.40, REG vs CHO P=0.60; Cholesterol: NR; Other components of diet differed significantly: Total fat (highest in REG and lowest in CHO), Carbohydrate (highest in CHO), Calcium (higher in REG compared to CHO) | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline and end of 12wk intervention; [underlined: TC], mmol/L, Mean (SD); REG vs RED: P=0.14; REG vs CHO: P=0.11; [underlined: LDL], mmol/L, Mean (SD); REG vs RED: P=0.42; REG vs CHO: P=0.17; [underlined: HDL], mmol/L, Mean (SD); REG vs RED: P=0.86; REG vs CHO: P=0.07; [underlined: Triglycerides], mmol/L, Mean (SD); REG vs RED: P=0.11; REG vs CHO: P=0.88; *No comparison between RED and CHO | Model adjustments:; Baseline outcome, age, sex, BMI, change in body fat; Limitations:; - None; Funding sources: Danish Dairy Research Foundation; Danish Agriculture and Food Council; National Dairy Council (U.S.); Dairy Farmers of Canada; Centre National Interprofessionel de l’Economie Laitiere; Dairy Australia; Nederlandse Zuivel Organisatie
Rozati, 2015 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4527272/) ^112^; RCT parallel, U.S.; Baseline N=44 Analytic N=41 (Attrition: 7%); Participant characteristics at baseline: Overweight or obese participants ≥65 years, ~70% Caucasian, 65% female; Summary of findings:; Olive oil intake, compared to intake of corn oil, soybean oil and butter combined, did not significantly change LDL, HDL cholesterol and triglycerides. | Intervention and comparator:; - Olive oil (average intake: 39 g/day, SEM=7) (n=20); - Control oil (10% Corn oil, 90% soybean oil) and butter; average intake 41 g/day, SEM=8) (n=21); [underlined: Fatty acid composition of olive oil and control oil + control butter, %:]; SFA: ~16.3 vs ~15.4 + ~62.8%; Oleic acid: 68.3 vs 22.7 + 30.7; LA: 10 vs 54.2 + 4.1; ALA: 0.7 vs 6.3 + 0.5; [underlined: Duration of intervention:] 3 months; [underlined: Compliance:] checklist of study oils consumed per week; dietary intake assessed via 3-day dietary record at baseline and 3 months; [underlined: Dietary intake for Intervention vs Control at 3 months, Mean (SD), g/day:]; SFA: 25 (2) vs 28 (3), P=0.33; MUFA: 44 (4) vs 29 (3), P<0.001; Oleic acid (18:1n9): 42 (4) vs 27 (3), P<0.001; PUFA: 15 (1) vs 28 (4), P=0.02; Cholesterol: NR; Other components of diet differed significantly: None | Outcomes and assessment methods:; Fasting blood lipids at 3 months; [underlined: LDL], mg/dL, Mean (SEM); Olive oil vs control: NS; [underlined: HDL], mg/dL, Mean (SEM); Olive oil vs control: NS; [underlined: Triglycerides], mg/dL, Mean (SEM); Olive oil vs control: NS | Model adjustments:; Age, sex and baseline value; Limitations:; - No information provided on randomization method; - No preregistered statistical analysis plan; Funding sources:; Deoleo Company (Spain), USDA
Rueda, 2013 (https://pubmed.ncbi.nlm.nih.gov/24352089) ^113^; RCT parallel, U.S.; Baseline N=73 Analytic N=48 (Attrition: 22%); Participant characteristics at baseline: Freshman in university (17-20y of age) with, on average, normal blood lipids and BMI at baseline.; Summary of findings:; Among freshman in university, consumption of 2 eggs for breakfast, 5 times per week for 14 weeks (which increased cholesterol and SFA intake), did not significantly change blood lipids compared to consumption of egg-free breakfasts. | Intervention and comparator:; - Egg breakfast containing one serving of egg (equivalent to 2 whole eggs) 5x/wk, n=27; - One serving of scrambled eggs: 170 calories, 12 g fat, 3.5 g saturated fat, 385 mg cholesterol; - Non-egg breakfast (5x/wk), n=21; - Sources: Pancakes (370 calories, 8 g fat, 0 g SFA and 0 g cholesterol) or ready-to-eat cereals (~115 calories, 1 g fat, 0 g SFA, 0 g cholesterol); [underlined: Duration of intervention:] 14 wk; [underlined: Compliance:] Assessed via university-issued ID cards (frequency of breakfast consumption), immediate recall of breakfast items consumed at weeks 1, 4, 7, 10, and 13 (3d each week), and food diaries at weeks 3 and 14; acceptable level of compliance reported; [underlined: Breakfast dietary intake at 13 wk for Egg vs Control, Mean (SD), kcal/d:]; SFA: 60 (16) vs 33 (15), P<0.0001; MUFA: NR; PUFA: NR; Cholesterol (mg/d): 404 (52) vs 68 (114), P<0.0001; Other components of diet differed significantly: Total fat and protein (both higher in Egg) | Outcomes and assessment methods:; Fasting blood lipids: Measured at 2wk, 8wk, 14wk; Differences at 2 wk, 8 wk, 14 wk and time*intervention interaction; [underlined: TC], mg/dL, Mean (SD); Egg vs no-egg breakfast: NS; [underlined: LDL], mg/dL, Mean (SD); Egg vs no-egg breakfast: NS; [underlined: HDL], mg/dL, Mean (SD); Egg vs no-egg breakfast: NS; [underlined: Triglycerides], mg/dL, Mean (SD); Egg vs no-egg breakfast: NS | Model adjustments:; None; Limitations:; - No information on randomization of allocation sequence; - Co-interventions (other dietary components) not balanced between groups; - No information on potential impact of missing data; - No preregistered statistical analysis plan; Funding sources:; American Egg Board
Tapsell, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/19570664) ^120^; RCT parallel, Australia; Baseline N=150 Analytic N=95 (Attrition: 37%); Participant characteristics at baseline:; Participants (men and women) aged mean 44 years who were overweight or obese; Summary of findings:; All groups significantly reduced total cholesterol, but the LC and PUFA groups had greater triglycerides reductions. HDL cholesterol increased in the LF-LC and LF-PUFA, but not in LF-PUFA-LC. | Intervention and comparators:; - Low-fat (LF) (n=26): isocaloric dietary advice, to target intake of 20% PRO, 50% CHO, and 30% FAT (5% PUFA, 15% MUFA, 10% SFA); - LF-PUFA (n=21): isocaloric dietary advice, to target foods high in PUFA, and 20% PRO, 50% CHO, and 30% FAT (10% PUFA, 10% MUFA, 10% SFA); - LF, low calorie (LFLC) (n=21): 2 MJ/d calorie restriction, to target intake of 20% PRO, 50% CHO, and 30% FAT (5% PUFA, 15% MUFA, 10% SFA); - LF-PUFA-LC (n=27): 2 MJ/d calorie restriction, to target foods high in PUFA, and 20% PRO, 50% CHO, and 30% FAT (10% PUFA, 10% MUFA, 10% SFA); [underlined: Duration of intervention:] 3 months; [underlined: Compliance]: measured at baseline and 3mo; [underlined: Dietary intake for Intervention diets: NR] | Outcomes and assessment methods:; Fasting blood lipids: Measured at baseline, 3mo; Change from baseline to 3mo (mean (SD), p-values for time, intervention, and diet effects (interaction effect); [underlined: TC (mmol/L):]; LF: −0.25 (0.3); LF-PUFA: −0.50 (1.2); LF-LC: −0.27 (0.5); LF-PUFA-LC: −0.30 (1.0); p=0.000, p=0.017, p=0.716 (0.711); [underlined: LDL (mmol/L):]; LF: −0.27 (0.4); LF-PUFA: −0.24 (0.6); LF-LC: −0.32 (0.4); LF-PUFA-LC: −0.44 (0.7); p=0.000, p=0.081, p=0.634 (0.533); [underlined: HDL (mmol/L):]; LF: 0.02 (0.2); LF-PUFA: 0.05 (0.1); LF-LC: 0.16 (0.3); LF-PUFA-LC: 0.00 (0.2); p=0.007, p=0.744, p=0.042 (0.069); [underlined: Triglycerides (mmol/L):]; LF: 0.09 (0.7); LF-PUFA: −0.47 (1.0); LF-LC: −0.26 (0.5); LF-PUFA-LC: −0.16 (0.4); p=0.008, p=0.091, p=0.056 (0.058) | Model adjustments:; None; Limitations:; - Weight loss trial; - No information on compliance reported; - No preregistered statistical analysis plan; Funding sources:; National Health and Medical Research Council of Australia
Utzschneider, 2013 (https://pubmed.ncbi.nlm.nih.gov/22849970) ^125^; RCT parallel, U.S.; Baseline N=49 Analytic N=35 (Attrition: 29%); Participant characteristics at baseline: Participants aged ~69 years, BMI ~27 with no differences in diets at baseline; Summary of findings:; Participants consuming high SFA diets from high-fat dairy and meat sources, compared to low SFA diet from low-fat dairy and mostly lean meats, had significantly higher total, LDL, and HDL cholesterol, and significantly lower triglycerides. | Intervention and comparator:; - Low SFA diet (n=20): Total fat 25%E, SFA 7%E; - Sources: low-fat and non-fat dairy, lean meats, bacon (to confuse participants to be able to guess which diet they were on); - High SFA diet (n=15): Total fat 45%, SFA 25%E; - Sources: butter, cheeses, fatty meats, cream; [underlined: Duration of intervention:] 4 wk; [underlined: Compliance:] weekly telephone calls and food record daily; all participants were compliant on macronutrient targets; [underlined: Dietary composition for Intervention vs Control at 4 wk, Mean (SEM), %E:]; SFA: 7.4 (0.2) vs 23.6 (0.2), P<0.001; MUFA: 21.2 (1.5) vs 32.6 (1.5), P<0.001; PUFA: 10.6 (0.7) vs 7.7 (0.3), P=0.50; Cholesterol: 108 (6) vs 354 (14), P<0.001; Other components of diet differed significantly: fat %E (higher in high SFA), carbohydrate %E (higher in low SFA), sugar (higher in low SFA), fructose (higher in low SFA), fiber (higher in low SFA), omega-3 FAs (higher in high SFA) | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 wk follow-up; [underlined: TC], mmol/L, Mean (SEM); Changes from baseline:; Low SFA: −0.59 (0.10); High SFA: 0.63 (0.17); P<0.001; [underlined: LDL], mmol/L, Mean (SEM); Changes from baseline:; Low SFA: −0.56 (0.08); High SFA: 0.52 (0.13); P<0.001; [underlined: HDL], mmol/L, Mean (SEM); Changes from baseline:; Low SFA: −0.17 (0.04); High SFA: 0.14 (0.07); P<0.001; [underlined: Triglycerides], mmol/L, Mean (SEM); Changes from baseline:; Low SFA: 0.31 (0.10); High SFA: −0.05 (0.06); P=0.01 | Model adjustments:; None; Limitations:; - No information provided on randomization method; - No preregistered statistical analysis plan; - Attrition >10%; - Other components of diet differed between groups (carbohydrate, sugar, fructose, fiber); Funding sources:; VA Office of Research and Development Medical Research Service; University of Washington Diagnostic Imaging Science Center
Vafeiadou, 2015 (https://pubmed.ncbi.nlm.nih.gov/26016869) ^126^; RCT parallel, DIVAS, United Kingdom; Baseline N=202 Analytic N=195 (Attrition: 3%); Participant characteristics at baseline: Non-smoking men (~28%) and women ~65 y with moderate CVD risk based on CVD risk score; Summary of findings:; Participants on SFA diet from butter had significantly increased changes in total cholesterol and LDL cholesterol, compared to the MUFA and n-6 PUFA diets. There were no significant effects on HDL cholesterol and triglycerides. | Intervention and comparators:; - SFA diet (n=65): 17%E SFA, 9%E MUFA, 9%E N-6 PUFA (Source: Butter); - MUFA diet (n=64): 11%E SFA, 19%E MUFA, 13%E n-6 PUFA (Source: refined olive oil, olive oil/rapeseed oil blended spread); - N-6 PUFA diet (n=66): 4%E SFA, 4%E MUFA, 10%E N-6 PUFA (Source: Safflower oil and spread); - All diets isoenergetic; [underlined: Duration of intervention:] 16 wk; [underlined: Compliance:] 4-day weighed diet diaries at 0, 8 and 16 weeks; compliance goals were met; [underlined: Change in dietary intake for SFA vs MUFA vs N-6 PUFA Diets, Mean (SEM), %total energy:]; SFA: 6.1 (0.4) vs −4.1 (0.4) vs −3.6 (0.4), P≤0.001 (differed between SFA diet and MUFA or n-6 PUFA); MUFA: −0.9 (0.3) vs 6.8 (0.4) vs 0.7 (0.4), P≤0.001 (different between all groups); n-6 PUFA: −2.3 (0.2) vs −0.5 (0.2) vs 5.5 (0.4), P≤0.001 (differed between all groups); n-3 PUFA: −0.20 (0.07) vs 0.08 (0.05) vs 0.04 (0.05), P≤0.001 (differed between SFA diet and MUFA or n-6 PUFA); Total PUFA: −2.5 (0.3) vs −0.4 (0.2) vs 5.5 (0.4), P≤0.001 (differed between all groups); Cholesterol (mg/day): 13 (14) vs −64 (15) vs −47 (13), P≤0.001 (differed between SFA diet and MUFA or n-6 PUFA); Other components of diet differed significantly: energy (Changes in energy intake was significantly different in SFA diet (−0.0 (0.2)) than MUFA (−0.7 (0.2)) or n-6 PUFA (−0.4 (0.2)) diet) | Outcomes and assessment methods:; Fasting blood lipids at 16 wk follow-up; [underlined: TC], mmol/L, Mean (SEM); Change:; SFA: 0.36 (0.08); MUFA: −0.07 (0.09); n-6 PUFA: −0.11 (0.09); SFA was significantly different from MUFA and n-6 PUFA P≤0.001; MUFA and n-6 PUFA did not significantly differ between groups; [underlined: LDL], mmol/L, Mean (SEM); Change:; SFA: 0.30 (0.07); MUFA: −0.09 (0.08) n-6; PUFA: −0.16 (0.07); SFA was significantly different from MUFA and n-6 PUFA P≤0.001; MUFA and n-6 PUFA did not significantly differ between groups; [underlined: HDL], mmol/L, Mean (SEM); SFA vs MUFA vs n-6 PUFA: NS; [underlined: Triglycerides], mmol/L, Mean (SEM); SFA vs MUFA vs n-6 PUFA: NS | Model adjustments:; Baseline values, BMI, age, sex; Limitations:; - No preregistered statistical analysis plan; Funding sources:; United Kingdom Food Standards Agency; Department of Health Policy Research Programme
van der Made, 2014 (https://pubmed.ncbi.nlm.nih.gov/24991045) ^127^; RCT parallel, Netherlands; Baseline N=101 Analytic N=88 (Attrition: 13%); Participant characteristics at baseline: Participants (~70% female) aged ~62 years, BMI ~26, who had early signs of macular degeneration; Summary of findings:; Consumption of 1.5 egg yolks daily for 1 year did not significantly change total, LDL, HDL cholesterol or triglycerides compared to control. | Intervention and comparator:; - Daily consumption of buttermilk drink (80 mL) containing one of the following:; - 1.5 egg yolks (n=45): 323 mg cholesterol, 33% SFA, 50% MUFA, 18% PUFA, 0.3% trans fat, 1.4 mg lutein; - Control (n=43): 2 mg cholesterol, 67% SFA, 26% MUFA, 4% PUFA, 3% trans fat, 0 g lutein; [underlined: Duration of intervention:] 1 year; [underlined: Compliance:] validated FFQ; good compliance reported; [underlined: Dietary intake for Intervention vs Control, Mean (SD), (%E):]; [underlined: SFA:] Intervention: Baseline 13 (3.1), Change +0.9 (3.0); Control: Baseline 14 (3.0), Change −0.2 (3.6), P=NS; [underlined: MUFA:] Intervention: Baseline 14 (4.0), Change +0.5 (3.5); Control: 14 (4.0), Change +1.1 (6.0), P=NS; [underlined: Oleic acid:] Intervention: Baseline 12 (4.0), Change −1.2 (3.6); Control: Baseline 12 (3.9), Change +1.2 (5.6), Change differed from control group P<0.05; [underlined: PUFA:] Intervention: Baseline 7.9 (3.2), Change +1.4 (3.3); Control: Baseline 8.2 (4.0), Change +0.3 (4.4), P=NS; Cholesterol (mg/d): Intervention: Baseline 245 (99), Follow-up 296 (106); Control: Baseline 217 (103), Change −12 (83), Change differed from control group P<0.05; Other components of diet differed significantly: None | Outcomes and assessment methods:; Fasting blood lipids at baseline and 1 year follow-up; Changes in lipids from baseline; [underlined: TC], mmol/L, Mean (SD); Egg yolk vs control: NS; [underlined: LDL], mmol/L, Mean (SD); Egg yolk vs control: NS; [underlined: HDL], mmol/L, Mean (SD); Egg yolk vs control: NS; [underlined: Triglycerides], mmol/L, Mean (SD); Egg yolk vs control: NS | Model adjustments:; None; Limitations:; - No information on randomization of allocation sequence; - No preregistered statistical analysis plan; Funding sources:; Europees Fonds voor Regionale Ontwikkeling; Dutch Ministry of Economic Affairs, the Province of Limburg; Newtricious R&D B.V.
Varady, 2011 (https://www.ncbi.nlm.nih.gov/pubmed/21251283) ^129^; RCT parallel, U.S.; Baseline N=20, Analytic N=17 (Attrition: 15%); Participant characteristics at baseline: Obese, BMI~33.5, 71% female, ~35 years, normal cholesterol, no diabetes, no CVD; Summary of findings:; In adults with obesity participating in a weight loss trial, there was no significant group differences in change over time for total, LDL- and HDL-cholesterol and triglycerides between those who followed a high fat diet versus a low fat diet for 6 weeks. | Intervention and comparator:; - High Fat: 60%E from total fat (26% SFA, 24% MUFA, 9% PUFA), n=9; - Low Fat: 25% E from total fat (7% SFA, 9% MUFA, 9% PUFA), n=8; - Energy restricted diets (25% baseline energy need) provided by researchers and distributed 3 times/week; - Both groups lost weight from baseline; [underlined: Duration of intervention:] 6 wk; [underlined: Compliance:] Subjects recorded foods added or missed from menu plan; noncompliant (>5% deviation) were excluded in analyses; [underlined: Diet composition for High Fat vs Low Fat: NR]; SFA (%E): 26% vs 7%; MUFA (%E): 24% vs 9%; PUFA: 9% vs 9%; Cholesterol (mg): 448 vs 299; Other components of diet differed significantly: Carbohydrate (%E): 5% vs 55%, Protein (%E): 35% vs 20%, Fiber (g): 11 vs 30 | Outcomes and assessment methods:; Fasting blood lipids: Assessed at study weeks 1 and 6; Comparing change between groups with time by treatment interaction; [underlined: TC], mg/dL, Mean (SD); High fat vs Low fat: P=NS; [underlined: LDL], mg/dL, Mean (SD); High fat vs Low fat: P=NS; [underlined: HDL], mg/dL, Mean (SD); High fat vs Low fat: P=NS; [underlined: Triglycerides], mg/dL, Mean (SD); High fat vs Low fat: P=NS | Model adjustments:; Time by treatment interaction; Limitations:; - Energy restricted diet; - >10% attrition; - No preregistered statistical analysis plan; Funding sources:; Kinesiology and Nutrition and Physical Therapy, University of Illinois, Chicago; NIH Clinical Research Center; NHLBI
Veum, 2017 (https://www.ncbi.nlm.nih.gov/pubmed/27903520) ^130^; RCT parallel, Norway; Baseline=46 Analytic N= 38 (Attrition: 17%); Participant characteristics at baseline: Men with abdominal obesity, 30-50 years, BMI >29, no diabetes; Summary of findings:; Among middle-aged men with abdominal obesity consuming moderately energy restricted diets for 12 weeks, a low-fat, high carbohydrate (LFHC) diet compared to a very high–fat, low-carbohydrate (VHFLC) diet, significantly reduced total cholesterol and LDL cholesterol and increased HDL cholesterol. There was no significant between-group difference in changes to triglyceride level. | Intervention and comparator:; - Very high–fat, low-carbohydrate (VHFLC): 73%E fat, 10%E carbohydrate, 17% protein (n=20); - Low-fat, high-carbohydrate (LFHC): 30%E fat and 53%E carbohydrate, 17% protein (n=18); - Modest isocaloric energy restricted diets; Diets emphasized low-processed, lower-glycemic foods; - Subjects received diet instruction, individual coaching as desired and food donations; [underlined: Duration of intervention:] 12 wk; [underlined: Compliance:] On-line dietary records 5-days/month and weight checks; noncompliant participants were excluded from analyses; Dietary intake for LFHC vs VHFLC, Mean (SD), (%):; SFA: 12.4 (1.1) vs 34.1 (3.1), P≤ 0.001; MUFA: 8.1 (1.0) vs 22.9 (1.9), P≤ 0.001; PUFA: 4.6 (1.0) vs 5.2 (1.0), P=NS; No significant difference in energy, protein (17%E) or PUFA; fiber intake significantly lower in the VHFLC group | Outcomes and assessment methods:; Fasting blood lipids: At baseline, 4 wk, 8 and 12 wk; Change from baseline to 12 wk, Mean (95% CI), p-values for time and group interaction; [underlined: TC], mmol/L; LFHC: −0.96 (−1.23, −0.69); VHFLC: +0.13 (−0.29, 0.55); LFHC vs VHFLC: P<0.001; [underlined: LDL], mmol/L; LFHC: −0.78 (−1.08, −0.49); VHFLC: +0.26 (−0.08, 0.60); LFHC vs VHFLC: P<0.001; [underlined: HDL], mmol/L; LFHC: −0.01 (−0.10, 0.07); VHFLC: +0.14 (0.06, 0.22); LFHC vs VHFLC: P=0.034; [underlined: Triglycerides], mmol/L; LFHC: −0.41 (−0.60, −0.21); VHFLC: −0.53 (−0.68, −0.37); LFHC vs VHFLC: P=NS | Model adjustments:; Age, baseline intake of energy, carbohydrate, added sugar, and cholesterol; Limitations:; - Energy restricted diet (subjects in both arms lost ~10.5kg); - Potential bias due to randomization process; - >10% attrition; - Preregistered statistical analysis plan describes 3 and 6 month outcome assessment (only short-term results reported); Funding sources:; Western Norway Regional Health Authority, Meltzerfondet; Bergen Medical Research Foundation; University of Bergen
Werner, 2013 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3720277/) ^132^; RCT parallel, Denmark; Baseline N=NR Analytic N=37 (Attrition: NR); Participant characteristics at baseline: Healthy participants from 50 to 70 years old (Mean ~62y), with normal BMI; Summary of findings:; There were no differences in total cholesterol, LDL, HDL cholesterol and triglycerides between participants who consumed butter from mountain-pasture-grazing cows and butter from conventionally fed cows. | Intervention and comparator:; - Replacement of 15%E of daily fat intake with:; - Butter from mountain-pasture grazing cows (n=19); different FA composition (20% less of cholesterol-raising SFAs than in control butter); - Butter from conventionally fed cows (n=18); [underlined: Duration of intervention:] 12 wk; [underlined: Compliance:] 3-day weighed food records at 6 wk; [underlined: Dietary intake after 6 wk for Intervention vs Control, Mean (SD), g/day:]; SFA: 16.0 (0.7) vs 15.8 (0.7), P=NS; MUFA: 10.2 (0.4) vs 10.6 (0.4), P=NS; PUFA: 4.0 (0.2) vs 3.6 (0.2), P=NS; Cholesterol: NR; Other components of diet differed significantly: None | Outcomes and assessment methods:; Differences in Fasting blood lipids; [underlined: TC]: NS; [underlined: LDL]: NS; [underlined: HDL]: NS; [underlined: Triglycerides]: NS | Model adjustments:; None; Limitations:; - No preregistered statistical analysis plan; Funding sources:; Strategic Research Council of Denmark, The Danish Dairy Research Foundation, Danish Cattle Federation and Arla Foods
Young, 2017 (https://www.ncbi.nlm.nih.gov/pubmed/28534446) ^133^; RCT parallel, U.S.; Baseline=78 Analytic N= 71 (Attrition: 9%); Participant characteristics at baseline: Healthy, ~26.6 y, 48% female, BMI ~23.7, 72% White, 14% African American, 10% Asian; Summary of findings:; Among young, healthy, normal weight adults, consumption of higher n-3 and lower n-6 diets compared to the standard military food plan for 10 weeks had no significant effect on blood lipid levels or between-group differences. | Intervention and comparators:; - Experimental Moderate (EXP-Mod): less n-6 (3.7%E) and more dietary n-3 (1.3%E) (n=27); - Experimental High (EXP-High): EXP-Mod diet plus 1 smoothie supplemented with 1000 mg n-3 (1.7%E)/day (n=28) (supplementation arm not included in this analysis); - Both experimental diets were lower in SFA, higher in MUFA (particularly oleic acid) than the control diet.; - Control: U.S. Military’s Standard Garrison Dining Facility Menu (n=23); - Participants consumed the same meals, but in intervention diets, high LA foods were replaced with high oleic acid/low LA and high n-3 fatty acid foods. Target foods included chicken, egg, oils, smoothies, and food ingredients.; - Most meals were prepared in a metabolic kitchen, diets were isocaloric; [underlined: Duration of intervention:] 10 wk; [underlined: Compliance:] Monitored by dietetic support staff and weight was monitored daily; high compliance reported; [underlined: Dietary intake for Control vs EXP-Mod vs EXP-High, Mean (SD), g/day:]; SFA: 16.6 (1.8) vs 14.4 (1.4) b vs 15.1 (1.3)b; MUFA: 20.7 (2·6) vs 30.5 (5·1)b vs 31.9 (5·4) b; PUFA, n-6: 22.8 (4.8) vs 8.1 (2.2)b vs 8.4 (2.1)b; PUFA, n-3: 2.8 (0.8) vs 2.9 (0.9) vs 3.9 (1.0)a,b; EPA+DPA+DHA (mg/d): 176 (73) vs 904 (482) b vs 1928 (736) a,b; Cholesterol: NR; No significant differences in macronutrient content of the diets. | Outcomes and assessment methods:; Fasting blood lipids: At baseline and after the feeding period.; Blood lipid levels at follow-up; [underlined: TC], mmol/L; Exp-Mod vs Control: P=NS; [underlined: LDL], mmol/L; Exp-Mod vs Control: P=NS; [underlined: HDL], mmol/L; Exp-Mod vs Control: P=NS; [underlined: Triglycerides], mmol/L; Exp-Mod vs Control: P=NS | Model adjustments:; None; Limitations:; - Preregistered statistical analysis plan does not include lipid outcomes; Funding sources:; U.S. Army Medical Research and Materiel Command; Intramural Program of the National Institute on Alcohol Abuse and Alcoholism
Yubero-Serrano, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/26561628) ^134^; RCT parallel (LIPGENE), Ireland, U.K., Norway, France, The Netherlands, Spain, Poland, Sweden; Baseline N=486 Analytic N=162 (Attrition: 66%); Participant characteristics at baseline: Participants (56% female) mean age 54 years with metabolic syndrome; Summary of findings:; In adults with metabolic syndrome, consuming a diet rich in SFA, compared to a diet rich in MUFA, for 12 weeks did not affect blood lipids. | Intervention and comparators:; - High SFA (HSFA) (n=39): high-fat (38% energy) SFA-rich diet (16% SFA, 12% MUFA, 6% PUFA); - High monounsaturated fatty acids (HMUFA) (n=38): high-fat (38% energy), MUFA-rich diet (8% SFA, 20% MUFA, 6% PUFA); Groups that did not meet inclusion criteria for review:; - Low-fat, high-complex carbohydrate (LFHCC) control (n=41): isoenergetic low-fat (28% energy), high-complex carbohydrate diet (8% SFA, 11% MUFA, 6% PUFA), with 1g/d high oleic sunflower oil supplement; - LFHCC n-3 (n=44): isoenergetic low-fat (28% energy), high-complex carbohydrate diet (8% SFA, 11% MUFA, 6% PUFA), with 1.24 g/d VLC n-3 PUFA supplement; [underlined: Duration of intervention:] 12 wk; [underlined: Compliance]: measured at weeks 6 and 12; [underlined: Dietary intake for HSFA, HMUFA, LFHCC, LFHCCn-3, Mean (SEM), %E:]; SFA: 17.50 (0.33), 10.38 (0.20), 8.56 (0.26), 8.65 (0.26); MUFA: 12.74 (0.26), 18.73 (0.37), 11.78 (0.30), 11.40 (0.28); PUFA: 6.25 (0.16), 6.66 (0.16), 6.00 (0.17), 5.67 (0.14); Cholesterol: NR; n-3 PUFA (g/d): 1.84 (0.12), 1.90 (0.12), 1.89 (0.16), 3.05 (0.14); Other components of diet differed significantly:; FAT: 39.83 (0.62), 38.92 (0.51), 29/63 (0.60), 29.12 (0.50); CHO: 41.24 (0.67), 42.07 (0.59), 49.35 (0.76), 50.22 (0.68); PRO: 17.42 (0.41), 16.87 (0.34), 19.18 (0.49), 18.34 (0.39) | Outcomes and assessment methods:; Fasting blood lipids: Measured at baseline, 12 wk; Between-group pre-post differences in intervention diet group, by tertile of insulin resistance (HOMA-IR); [underlined: Tertile 1 (HOMA-IR<1.90)]:; - TC: NS; - LDL: NS; - HDL: NS; - Triglycerides: NS; [underlined: Tertile 2 (HOMA-IR 1.90-2.93)]:; - TC: NS; - LDL: NS; - HDL: NS; - Triglycerides: NS; [underlined: Tertile 3 (HOMA-IR >2.93)]:; - TC: NS; - LDL: NS; - HDL: NS; - Triglycerides: NS | Model adjustments:; None; Limitations:; - Information on compliance NR; - No preregistered statistical analysis plan; Funding sources:; EU 6 Framework Food Safety & Quality Programme
RCT Crossover Design
Abdullah, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/25609231) ^39^; RCT multi-center crossover, Canada; Baseline N=137 Analytic N=124 (Attrition: 9%); Participant characteristics at baseline: Healthy adults aged ~39, SD=16.4 years with mean BMI of 25.7, CVD free, no diabetes, no smoking; Summary of findings:; Intake of 3 servings/d of conventional dairy products compared to a dairy free diet for 4 weeks significantly increased LDL cholesterol but did not have a significant effect on total and HDL cholesterol, or triglycerides. | Intervention and comparator:; - Diet with dairy products (total n=114); - Sources: 3 servings/day of commercial dairy including 1% fat milk, 1.5% fat yogurt and 34% fat cheese; - Dairy-free diet (total n=117); - Sources: Energy-equivalent control including fruit and vegetable juice, cashews and a cookie; [underlined: Duration of intervention:] 4 wk each diet (4-8 wk washout period); [underlined: Compliance:] validated Web-based FFQ and weekly report of daily consumption of dairy products; good compliance evident by FFQ mean 3.5 servings/d net difference between the intake of dairy and control products (P<0.0001); [underlined: Dietary intake for Intervention vs Control, Mean (95%CI):]; SFA (%E): 10.7 (10.4, 11.1) vs 8.5 (8.2, 8.8), P<0.0001; MUFA(%E): 12.0 (11.6, 12.5) vs 14.0 (13.4, 14.6), P<0.0001; PUFA(%E): 5.3 (5.1, 5.6) vs 7.1 (6.9, 7.4), P<0.0001; Cholesterol (mg): 209.8 (193.8, 227.1) vs 168.0 (150.0, 188.3), P<0.0001; Trans FA: NS; Other components of diet differed: carbohydrate, fiber, protein, calcium and vitamin D | Outcomes and assessment methods:; Fasting blood lipids at end of each dietary phase (4 wk follow-up); [underlined: TC], mmol/L, Control vs Dairy, Mean (SE); Intervention: 5.08 (0.08); Control: 5.00 (0.08); Between-group: P=0.07; [underlined: LDL], mmol/L, Control vs Dairy, Mean (SE); Intervention: 2.99 (0.08); Control: 2.91 (0.08); Between-group: P=0.04; [underlined: HDL,] mmol/L, Control vs Dairy, Mean (SE); Intervention: 1.53 (0.4); Control: 1.53 (0.04); Between-group: P=0.92; [underlined: Triglycerides], mmol/L, Control; Dairy, Mean (SE); Intervention: 1.23 (0.05); Control: 1.23 (0.06); Between-group: P=0.69 | Model adjustments:; None; Limitations:; - No preregistered statistical analysis plan; Funding sources:; Dairy Research Cluster Initiative (Agriculture and Agri-Food Canada, Dairy Farmers of Canada, the Canadian Dairy Network, and the Canadian Dairy Commission)
Alphonse, 2017 (https://pubmed.ncbi.nlm.nih.gov/28112077) ^42^; RCT crossover, Canada; Baseline N=55 Analytic N=49 (Attrition: 11%); Participant characteristics at baseline: Participants (57% female) with normal or slightly elevated cholesterol aged ~33 years, majority overweight, without history of CVD, CHF or diabetes; Summary of findings:; Egg yolk cholesterol, compared to plant sterols, significantly increased total cholesterol, LDL and HDL cholesterol. Egg yolk cholesterol, compared to control (no cholesterol), significantly increased total cholesterol and HDL cholesterol, but not LDL cholesterol and triglycerides. There were no differences in blood lipids between plant sterols and controls (no plant sterol). | Intervention and comparators:; - Daily milkshake (240 mL) containing one of following:; - Egg yolk cholesterol (600 mg); - Plant sterols (2 g); - Control (no cholesterol and plant sterol); - Participants advised to maintain typical diet and physical activity levels; [underlined: Duration of intervention:] 4 wk each diet (4 wk washout); [underlined: Compliance:] weekly checklists, 3-day food records; all included participants completed all three phases and study requirements; [underlined: Dietary intake:] NR | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 wk follow-up; [underlined: TC], mmol/L, Mean (SEM); Levels at 4wk:; Egg cholesterol: 5.03 (0.13); Plant sterols: 4.78 (0.14); Control: 4.76 (0.14); Change from control, mean % (SEM); Egg cholesterol: +4.76 (1.42); Plant sterol: −1.58 (1.43); Egg cholesterol vs plant sterols: P<0.05; Egg cholesterol vs control: P<0.05; [underlined: LDL], mmol/L, Mean (SEM); Levels at 4wk:; Egg cholesterol: 2.96 (0.13); Plant sterols: 2.72 (0.13); Control: 2.85 (0.13); Change from control, mean % (SEM); Egg cholesterol: +5.40 (2.61); Plant sterol: −2.86 (2.39); Egg cholesterol vs plant sterols: P<0.05; Egg cholesterol vs control: NS; [underlined: HDL], mmol/L, Mean (SEM); Levels at 4wk:; Egg cholesterol: 1.53 (0.06); Plant sterols: 1.45 (0.06); Control: 1.44 (0.06); Change from control, mean % (SEM); Egg cholesterol: +6.64 (2.06); Plant sterol: +1.28 (1.85); Egg cholesterol vs plant sterols: P<0.05; Egg cholesterol vs control: P<0.05; [underlined: Triglycerides], mmol/L, Mean (SEM); Levels at 4wk:; Egg cholesterol: 5.03 (0.13); Plant sterols: 4.78 (0.14); Control: 4.76 (0.14); Change from control, mean (%); Egg cholesterol: +1.55 (3.12); Plant sterol: +7.95 (4.97); Egg cholesterol vs plant sterols: NS; Egg cholesterol vs control: NS | Model adjustments:; Treatment, sequence and sex; Limitations:; - No information on randomization of allocation sequence; - No preregistered statistical analysis plan; Funding sources:; Dairy Farmers of Canada; Agri-Food Research and Development Initiative
Andraski, 2019 (https://pubmed.ncbi.nlm.nih.gov/31554421/) ^43^; RCT crossover, U.S.; Baseline=NR Analytic N=12 (Attrition: NR); Participant characteristics at baseline: Overweight, BMI ~30.7, low HDL cholesterol (mean 44.4 mg/dl), ~42 y, 67% female; Summary of findings:; Consumption of a high-fat, high-MUFA diet compared to a low-fat, high carbohydrate diet had no significant between-group differences in changes to blood lipids in overweight adults with low HDL cholesterol. | Intervention diets:; - High fat (high MUFA): 40% fat (23% MUFA, 7% PUFA, 10% SFA), 45% CHO, 15% protein, 180mg cholesterol; - MUFA from vegetable oil and nuts; - Low fat (high carbohydrate): 20% fat (8% MUFA, 7% PUFA, 5% SFA), 65% CHO, 15% protein, 90 mg cholesterol; - Carbohydrate mainly from whole grains; - Isocaloric diets; all food and beverages provided by researchers; [underlined: Duration of intervention:] 32 days (3 wk washout, consumed self-selected diet); [underlined: Compliance:] NR; [underlined: Dietary intake for Low fat vs High fat diet]: NR | Outcomes and assessment methods:; Fasting blood lipids: At baseline and after each feeding period.; Difference at follow-up; [underlined: TC,] mmol/L; High fat vs low fat: NS; [underlined: LDL], mmol/L; High fat vs low fat: NS; [underlined: HDL], mmol/L; High fat vs low fat: NS; [underlined: Triglycerides,] mmol/L; High fat vs low fat: NS | Model adjustments:; None; Limitations:; - No information provided about randomization or period effects; - No data available to asses attrition rate; - No information provided about diet compliance; - Potential bias from missing data; - No preregistered statistical analysis plan for most blood lipid outcomes; Funding sources:; National Institutes of Health; Kowa Company Ltd; American Heart Association
Baer, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/30753323) ^45^; RCT crossover, U.S.; Baseline N=42 Analytic N=40 (Attrition: 5%); Participant characteristics at baseline: Adults ~57y of age with BMI ~29 and total blood cholesterol ~206 mg/dL at baseline.; Summary of findings:; Consumption of 42 g/d of cashews for 4 weeks, which increased MUFA intake, did not significantly change blood lipids compared to a cashew free diet. | Intervention and comparator diets:; - Base diet with cashews (42g/d) daily; - Sources: cashews; - Control: Base diet without cashews; - Sources: NA; - Two treatment phases were isocaloric, other study foods reduced proportionately to incorporate cashews; - All food provided to participants during study period; [underlined: Duration of intervention:] 4 wk (1 wk washout); [underlined: Compliance:] Monitored by dining facility staff for breakfast and dinner on weekdays and additionally assessed by checking food items and food weights.; [underlined: Diet composition for Cashew vs Control, Mean, %E:]; SFA: ~11 vs ~11, P=NR; MUFA: ~11 vs ~9, P=NR; PUFA: ~8 vs ~7, P=NR; Cholesterol: NR; Other components of diet differed significantly: Total fat (higher in Cashew), CHO (lower in Cashew) | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured in duplicate at baseline and 4 wk; Levels at 4 wk follow-up; [underlined: TC], mg/dL; Cashew vs Control: P=NS; [underlined: LDL], mg/dL; Cashew vs Control: P=NS; [underlined: HDL], mg/dL; Cashew vs Control: P=NS; [underlined: Triglycerides], mg/dL; Cashew vs Control: P=NS | Model adjustments:; Baseline blood lipid, BMI, age, sex, treatment sequence, treatment period; Limitations:; - Only one week washout between interventions; Funding sources:; USDA Agricultural Research Service; Global Cashew Council; International Nut and Dried Fruit Council
Barbour, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/26404365) ^46^; RCT crossover, Australia; Baseline N=69 Analytic N=61 (Attrition: 12%); Participant characteristics at baseline: Nonsmoking adults ~65y of age with overweight or obesity without hypertension or CVD; Summary of findings:; Consuming high oleic peanuts for 12 weeks (which increased MUFA intake) did not change blood lipids compared to a nut free diet. | Intervention and comparator diets:; - High oleic peanuts, 84g/d (men) or 56g/d (women) 6d/wk; - Sources: roasted, unsalted high oleic peanuts; - Control: Nut-free regular diet; - Sources: NA; [underlined: Duration of intervention:] 12 wk each diet (no washout period); [underlined: Compliance:] Monitored via diet diaries. 85% (women) and 80% (men) of peanuts consumed; [underlined: Total diet intake at 12 wk for Peanuts vs Control, Mean (SD), g/d:]; SFA: 31.8 (8.7) vs 29.6 (9.7), P=NS; MUFA: 47.5 (11.3) vs 25.2 (7.7), P<0.001; PUFA: 11.2 (3.3) vs 9.8 (3.3), P<0.001; Cholesterol: NR; Other components of diet differed significantly: Total fat and protein, fiber, and total energy intake (all higher in Peanut) | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline and 12 wk; Difference at follow-up; [underlined: TC], mmol/L; Peanut vs Control: P=NS; [underlined: LDL], mmol/L; Peanut vs Control: P=NS; [underlined: HDL], mmol/L; Peanut vs Control: P=NS; [underlined: Triglycerides], mmol/L; Peanut vs Control: P=NS | Model adjustments:; Baseline blood lipid; Limitations:; - None to report; Funding sources:; Australian Research Council; Peanut Company of Australia
Bowen, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/30773586) ^54^; RCT crossover, COMIT II, Canada and U.S.; Baseline N=174 Analytic N=119 (Attrition: 32%); Participant characteristics at baseline: Adults (63% female) with or at risk for metabolic syndrome, mean age ~44 y, BMI~32, ~30% with dyslipidemia; Summary of findings:; Consumption of canola oil or HOCO increased MUFA and decreased SFA intake, and significantly lowered blood total- and LDL cholesterol compared to a consumption of a control oil configured to mimic a Western-style diet over 6 weeks in adults for 6 weeks with metabolic syndrome. | Intervention and Comparators:; - Participants consumed smoothies (2/d) containing one of the following oils:; - Canola oil; - High-oleic acid canola oil (HOCO); - Control oil; - Sources:49% ghee, 29% safflower oil, 14% flaxseed oil, and 8% coconut oil; [underlined: Types of fat in canola oil vs HOCO vs Control, %:]; SFA 6.56 vs 6.43 vs 12.26; MUFA: 17.45 vs 19.11 vs 10.50; Oleic acid: 15.55 vs 17.86 vs 5.92; PUFA: 9.21 vs 7.02 vs 9.96; ALA: 2.10 vs 0.76 vs 1.73; - Oils provided ~18% of total energy for all calorie levels (e.g., for a 3,000 kcal diet, 60 g of oil was provided); - Controlled-feeding study: all meals/snacks provided by researchers; [underlined: Duration of intervention:] 6 wk each feeding period (≥4-wk washout periods); [underlined: Compliance:] NR; [underlined: Dietary intake for Canola oil vs HOCO vs Control, Mean (SD), g/day:] NR; Three experimental diets were identical in %E from macronutrients. | Outcomes and assessment methods:; Fasting blood lipids assessed at baseline (day 1 and 2) and the endpoint (days 41 and 42); Endpoint-to-endpoint comparisons; [underlined: TC], mmol/L, Mean (SEM); Levels at 6 wk:; Canola: 4.54 (0.04); HOCO: 4.58 (0.04); Control: 4.74 (0.04); Canola vs Control P<0.0001; HOCO vs Control P = 0.002; Canola vs HOCO: NS; Group difference: P<0.0001; [underlined: LDL], mmol/L, Mean (SEM); Levels at 6 wk:; Canola: 2.64 (0.04); HOCO: 2.67 (0.04); Control: 2.83 (0.04); Canola vs Control P<0.0001; HOCO vs Control P = 0.0002; Canola vs HOCO: NS; Group difference: P<0.0001; [underlined: HDL], mmol/L, Mean (SEM); Group difference: NS; [underlined: Triglycerides], mmol/L, Mean (SEM); Group difference: NS | Model adjustments:; Diet specific baseline value; Limitations:; - No information on compliance; - Potential missing data bias due to not statistically accounting for missing data; - No preregistered statistical analysis plan; Funding sources:; Agriculture and Agri-Food Canada; the Canola Council of Canada, Alberta Canola; SaskCanola; Dow Agro Sciences; Manitoba Canola Growers; the National Center for Research Resources; NIH
Brassard, 2017 (https://www.ncbi.nlm.nih.gov/pubmed/28251937) ^55^; RCT crossover, Canada; Baseline N=103 Analytic N=92 (Attrition: 11%); Participant characteristics at baseline: Predominantly white, overweight or obese men and women ~39y of age with high waist circumference and HDL concentrations below 75^th^ percentile.; Summary of findings:; Diets rich in SFA from cheese or butter, compared to diets rich in MUFAs, PUFAs or CHOs, increased total and LDL cholesterol. Compared to a diet higher in CHO, diets rich in SFA from cheese or butter increased HDL cholesterol. Triglycerides were increased by a diet rich in SFA from cheese compared to diets rich in SFA from butter or in PUFA, but triglycerides were reduced by a diet rich in SFA from butter compared to a diet higher in CHO. | Intervention and comparator diets:; - Diet rich in SFAs from cheese; - Sources: cheese; - Diet rich in SFAs from butter; - Sources: butter; - Diet rich in MUFAs; - Sources: refined olive oil; - Diet rich in PUFAs; - Sources: corn oil; - CHO: High-carbohydrate, low-fat diet; - Sources: NR; - All FA diets: 32%E FA, 52%E CHO, 16%E protein; - High CHO, low fat diet: 25%E FA, 59%E CHO, 16% protein; - Each participant consumed 5 isoenergetic diets for 4 wk each separated by ≥24 d washouts. 3 meals & 1 snack per day provided to participants; [underlined: Duration of intervention:] 4 wk each diet (washout ≥24 days); [underlined: Compliance:] Weekly checklist of study foods consumed and not consumed, self-reported compliance : 98.7% SD = 2.4%; [underlined: Nutritional composition of intervention diets for Cheese vs Butter vs MUFA vs PUFA vs CHO, Mean, %E:]; SFA: 12.6 vs 12.4 vs 5.8 vs 5.8 vs 5.8; MUFA: 12.5 vs 12.3 vs 19.6 vs 12.6 vs 12.6; PUFA: 4.8 vs 4.8 vs 4.8 vs 11.5 vs 4.8; Cholesterol: All ~272mg/2500kcal; Other components of diet differed significantly: CHOs higher (59%) in CHO diet vs all others (~52%); Calcium (higher in the cheese than other groups) | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured in duplicate at end of 4wk intervention period; [underlined: TC], mmol/L, Mean (SD); Cheese: 5.00 (0.94); vs MUFA, PUFA or CHO: p<0.05; Butter: 5.10 (0.95); vs MUFA, PUFA or CHO: p<0.05; MUFA: 4.82 (0.89); PUFA: 4.60 (0.81); CHO: 4.89 (0.92); P-between diets: <0.0001; [underlined: LDL], mmol/L, Mean (SD); Cheese (ref): 3.19 (0.81); vs MUFA, PUFA or CHO: p<0.05; Butter (ref): 3.30 (0.84); vs MUFA, PUFA or CHO: p<0.05; MUFA: 3.03 (0.78); PUFA: 2.84 (0.69); CHO: 3.11 (0.79); P-between diets: <0.0001; [underlined: HDL], mmol/L, Mean (SD); Cheese: 1.10 (0.19); vs CHO, p<0.05; Butter: 1.11 (0.21); vs CHO, p<0.05; MUFA: 1.10 (0.19); PUFA: 1.10 (0.20); CHO: 1.06 (0.19); P-between diets: 0.0051; [underlined: Triglycerides], mmol/L, Mean (SD); Cheese: 1.43 (0.70); vs Butter or PUFA, p<0.05; Butter: 1.36 (0.73); vs CHO, p<0.05; MUFA: 1.38 (0.67); PUFA: 1.30 (0.62); vs Cheese, p<0.05; CHO: 1.46 (0.71); vs Butter, p<0.05; P-between diets: 0.0007; *No comparison made between CHO, MUFA, and PUFA diets because were not primary objectives of study | Model adjustments:; When variable p<0.05: baseline blood lipid value, sex, age, BMI, center, sequence, WHR or waist circumference, ethnicity; Limitations:; - No information provided on randomization method; - No preregistered statistical analysis plan for most blood lipid outcomes; Funding sources:; Dairy Research Cluster Initiative (Agriculture and Agri-Food Canada, Dairy Farmers of Canada, the Canadian Dairy Network, the Canadian Dairy Commission)
Burns-Whitmore, 2014 (https://pubmed.ncbi.nlm.nih.gov/24673793) ^56^; RCT crossover, U.S.; Baseline N=26, Analytic N=20 (Attrition: 23%); Participant characteristics at baseline: Nonsmoking, healthy lacto-ovo vegetarians (80% female, 50% White) ~38y of age with normal blood lipids and BMI ~23.; Summary of findings:; Among healthy lacto-ovo vegetarians, consumption of walnuts for 8 weeks (which increased n-6 PUFA and ALA intake, and decreased dietary cholesterol intake) reduced total blood cholesterol and triglycerides compared to consumption of standard or n-3 FA enriched eggs. Blood lipids did not vary significantly between standard egg and n-3 FA enriched egg. | Intervention and comparators:; - n-3 FA enriched egg (6/wk); - Sources: eggs from chickens fed diet containing flaxseed; - Walnuts (28.4g, 6/wk); - Sources: walnuts; - Standard egg (6/wk); - Sources: eggs; [underlined: Duration of intervention:] 8 wk each diet (washout: 4 wk); [underlined: Compliance:] Monitored via counseling with dietitian, daily diary to record deviations in food intake, and 3, 24hr recalls per treatment period; compliance met through dietary intake; [underlined: Total dietary intake for n-3 enriched egg vs walnuts vs standard egg, Mean, %E:]; SFA: 7.71 vs 7.86 vs 7.55, P=NS; MUFA: 10.4 vs 10.5 vs 10.4, P=NS; PUFA: 6.53 vs 11.7 vs 6.98, P<0.0001 (walnut vs n-3 enriched egg or standard egg); n-6 PUFA: 5.21 vs 9.84 vs 5.84, P<0.0001 (walnut vs n-3 enriched egg or standard egg); LA: 5.16 vs 9.84 vs 5.79, P<0.0001 (walnut vs n-3 enriched egg or standard egg); AA: 0.54 vs 0.53 vs 0.50, P<0.0001 (all differ); n-3 PUFA: 0.55 vs 1.61 vs 0.66, P<0.0001 (walnut vs n-3 enriched egg or standard egg); ALA: 0.49 vs 1.61 vs 0.64, P<0.0001 (walnut vs n-3 enriched egg or standard egg); EPA: 0.06 vs 0.00 vs 0.00, P<0.0001 (n-3 enriched egg vs walnuts or standard egg); DHA: 0.06 vs 0.00 vs 0.00, P<0.0001 (n-3 enriched egg vs walnuts or standard egg); Cholesterol (mg/d): 214 vs 46 vs 136, P<0.0002 (walnut vs n-3 enriched egg or standard egg); Other components of diet differed significantly: Protein (lower in walnut) | Outcomes and assessment methods:; Fasting blood lipids: Measured at baseline and 4 wk; Comparison between baseline adjusted values at 4 wk; [underlined: TC], mmol/L, Mean (95% CI); Standard egg: 5.09 (4.92, 5.26); n-3 enriched egg: 4.96 (4.79, 5.12); Walnuts: 4.77 (4.60, 4.94); Walnut vs Standard egg (ref): P<0.05; n-3 enriched egg vs Walnut or Standard egg: P=NS; [underlined: LDL], mmol/L; Standard egg vs n-3 enriched egg vs; Walnut: All P=NS; [underlined: HDL], mmol/L; Standard egg vs n-3 enriched egg vs; Walnut: All P=NS; [underlined: Triglycerides], mmol/L; Standard egg: 1.12 (1.00, 1.26); n-3 enriched egg: 0.97 (0.87, 1.08); Walnuts: 0.92 (0.83, 1.03); Walnut vs Standard egg (ref): P<0.05; n-3 enriched egg vs Walnut or Standard egg: P=NS | Model adjustments:; Period effect, baseline values; Limitations:; - No information on randomization of allocation sequence; - No information on missing data by intervention sequence; - No preregistered statistical analysis plan; Funding sources:; American Egg Board Fellowship; Agriculture Research Institute (Grant) from California State Polytechnic University, Pomona; California Walnut Commission (donation of walnuts); Chino Valley Ranchers (donation of eggs)
Cheng, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/30160543) ^57^; RCT crossover, China; Baseline N=72 Analytic N=67 (Attrition: 7%); Participant characteristics at baseline: Healthy Chinese participants (~50% female) aged ~23 years, with normal BMI and no history of CVD, hypertension or diabetes; Summary of findings:; Consumption of palm olein, compared to cocoa butter and extra virgin olive oil resulted in significantly lower triglycerides in young Chinese adults. No other significant differences in blood lipids were observed. | Intervention and comparators:; - Palm olein (35% SFA); - Cocoa butter (64% SFA); - Extra virgin olive oil (17% SFA); - Participants consumed standardized Chinese meals provided by researchers, enriched with one of the test oils; - Each test oil accounted for ~40% of total fat intake and ~11.3% total energy intake; [underlined: Fatty acid composition of palm olein, CB and EVOO, g%:]; SFA: 34.5 vs 64.4 vs 17.2 (EVOO < PO and CB, P<0.01); Palmitic acid: 29.4 vs 26.2 vs 13; Stearic acid: 3.4 vs 37.1 vs 3.9; MUFA: 50.7 vs 33.1 vs 77.5 (EVOO > PO and CB, P<0.01); Oleic acid: 50.3 vs 33.1 vs 76.3; PUFA: 14.8 vs 2.5 vs 5.3, P>0.05; ALA: 0.3 vs 0 vs 0.7; LA: 14.5 vs 2.5 vs 4.6; [underlined: Duration of intervention:] 4 wk each dietary period (2 week run-in and 2-wk washout periods); [underlined: Compliance:] All participants dined in cafeteria and researchers supervised compliance and intake behavior; all participants adhered to diet “closely”; [underlined: Dietary intake for palm olein, cocoa butter, extra virgin olive oil, Mean (SD), g/day:]; SFA: 18.2 (1.6) vs 24.7 (1.3) vs 13.9 (0.7), between all groups: P<0.05; MUFA: 24.8 (1.5) vs 20.8 (1.6) vs 31.2 (0.7), between all groups: P<0.05; PUFA: 9.7 (1.0) vs 7.7 (1.6) vs 9.2 (1.1), P=NS between groups; Cholesterol: 489.1 (75.3) vs 498.2 (113.9) vs 493.6 (99.3), P=NS; Other components of diet differed significantly: None | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 wk follow-up after each experimental diet; Levels at 4 wk follow-up; [underlined: TC], mmol/L, Mean (SD); Palm olein vs cocoa butter vs EVOO: NS; [underlined: LDL], mmol/L, Mean (SD); Palm olein vs cocoa butter vs EVOO: NS; [underlined: HDL], mmol/L, Mean (SD); Palm olein vs cocoa butter vs EVOO: NS; [underlined: Triglycerides], mmol/L, Mean (SD); Palm olein: 0.81 (0.28); Cocoa butter: 0.84 (0.31); EVOO: 0.88 (0.31); Palm olein vs cocoa butter: P<0.05; Palm olein vs EVOO: P<0.05; Cocoa butter vs EVOO: NS | Model adjustments:; Baseline indices, age, gender; Limitations:; - No preregistered statistical analysis plan; Funding sources:; Nutrition Fund Chinese Nutrition Society; Fundamental Research Funds for the Central Universities; Research Innovation Program for College Postgraduates in Jiangsu Province; National Key Project of Research and Development Plan
Chinwong, 2017 (https://www.ncbi.nlm.nih.gov/pubmed/29387131) ^58^; RCT crossover, Thailand; Baseline N=34 Analytic N=32 (Attrition: 6%); Participant characteristics at baseline: Participants (50% female) aged ~21 years with normal serum lipid levels at baseline, BMI ~21; Summary of findings:; Consumption of coconut oil (15 mL twice a day), compared to a 2% carboxymethylcellulose solution, significantly increased HDL cholesterol, but no other significant differences in changes in blood lipids were observed. | Intervention and comparator:; - Virgin coconut oil (15 mL/day x 2 times/day): lauric acid (12%) 50%, myristic acid (C14:0) 18%, caprylic acid (C8:0) 9%, palmitic acid (C16:0) 8%; - 2% carboxymethylcellulose (CMC) solution (15 mL/day x 2 times/day); [underlined: Duration of intervention:] 8 wk each dietary period (washout: 8 wk); [underlined: Compliance:] daily food record throughout study period; participant interview; compliance NR; [underlined: Dietary intake for Intervention vs Control:] NR | Outcomes and assessment methods:; Fasting blood lipids at baseline and 24 wk follow-up; [underlined: TC], mg/dL, Mean (SD); Difference in change: VCO vs control: NS; [underlined: LDL], mg/dL, Mean (SD); Difference in change: VCO vs control: NS; [underlined: HDL], mg/dL, Mean (SD); Baseline to follow-up; VCO: 60.3 (9.2) to 64.2 (9.9); Control: 60.8 to 59.0; Change:; VCO: 3.91 (6.34); Control: −1.81 (6.49); Difference in change: 5.72 (9.01), P=0.001; [underlined: Triglycerides], mg/dL, Mean (SD); Difference in change: VCO vs control: NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - No information on compliance; - No preregistered statistical analysis plan; Funding sources:; Thailand Research Fund
Choi, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/29663407) ^60^; RCT crossover, U.S.; Baseline N=15 Analytic N=12 (Attrition: 20%); Participant characteristics at baseline: Men ~68y and post-menopausal women ~61y with BMI ~27; Summary of findings:; Consumption of 18% fat ground-beef patties (less oleic acid and less dietary cholesterol), compared to 25% fat ground beef patties (more oleic acid and more dietary cholesterol) did not result in any changes in total blood cholesterol, LDL, HDL cholesterol, or triglycerides. | Intervention and comparator:; - [underlined: 18% fat:] Ground-beef patties containing 18% total fat (5 per week) (intervention first: n=6): SFA: 7.6 g/patty; MUFA: 9.2 g/patty; trans fat: 0.8 g/patty; each patty = 114 grams (~4 ounces) previously reported; - [underlined: 25% fat:] Ground-beef patties containing 25% total fat (5 per week) (control first: n=6): SFA: 11.9 g/patty; MUFA: 11.3 g/patty; trans fat: 1.6 g/patty; [underlined: Duration of intervention:] 5 wk (washout 4 wk); [underlined: Compliance:] 4-day record; [underlined: Dietary intake for Intervention (18% fat patty) vs Control (25% fat patty) after each intervention period, Mean (SE), g/day:]; SFA: 28 (4) vs 29 (3); MUFA: 26 (4) vs 28 (2); Oleic acid: 21 (3) vs 24 (2), P<0.05 (time*treatment); LA: 12 (3) vs 10 (1); ALA: 0.8 (0.1) vs 0.9 (0.1); EPA: 0.01 (0.01) vs 0.05 (0.02); DHA: 0.01 (0.01) vs 0.11 (0.05); PUFA: 13 (3) vs 12 (1); Cholesterol (mg/day): 241 (45) vs 310 (61), P<0.05 (time*treatment); Other components of diet differed significantly: None | Outcomes and assessment methods:; Fasting blood lipids at baseline and 5 wk follow-up; Two-factor (time and treatment) repeated-measures ANOVA; [underlined: TC], mmol/L, Mean (SE); 18% fat vs 25% fat: NS; [underlined: LDL], mmol/L, Mean (SE); 18% fat vs 25% fat: NS; [underlined: HDL], mmol/L, Mean (SE); 18% fat vs 25% fat: NS; [underlined: Triglycerides], mmol/L, Mean (SE); 18% fat vs 25% fat: NS | Model adjustments:; None; Limitations:; - No information on randomization of allocation sequence; - No information on compliance; - No information on whether missing data was different between groups; - No preregistered statistical analysis plan; Funding sources:; Texas AgriLife Research
Dawczynski, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/20304540) ^62^; RCT crossover, Germany; Baseline N=51 Analytic N=40 (Attrition: 22%); Participant characteristics at baseline: Healthy adults aged 59.2, SD= 6.0 years with mean BMI of 29.7, no CVD, no diabetes, mildly hypertriglyceridemic (TAG: ≥1.5 mmol/L); Summary of findings:; The consumption of dairy products supplemented with 3g/d n-3 LC-PUFA for 15 weeks compared to a placebo significantly decreased blood triglyceride and increased HDL-cholesterol and had no effect on total and LDL cholesterol in adults with mild hypertriglyceridemia. | Intervention and comparator:; - 3g n- 3 LC-PUFA/d provided via supplemented dairy products (~40 g fat daily).; - Sources: 200 g yogurt (3.8% fat), 30 g cheese (~ 50% fat), and 20-30 g butter; milk fat partially replaced by fish oil/rapeseed oil (not detectable) + 0.1 g/100 g vit E; - Placebo: dairy products not supplemented; - Sources: Same as above, un-supplemented; [underlined: Duration of intervention:] 15 wk (10 wk washout period); [underlined: Compliance:] 9 persons excluded for non-compliance (increase in erythrocyte membrane EPA <50% after 15wk intervention); EPA increase in “consumers” 282%, SD=153; [underlined: Dietary intake for Intervention vs Control, Mean (SD), g/d:]; SFA: 33.8 (9.92) vs 37.9 (11.2), P≤0.05; MUFA: 25.4 (8.70) vs 26.3 (9.63), P: NS; PUFA: 13.5 (3.74) vs 11.0 (3.69), P≤0.01; The intake of AA, EPA, DHA, MUFA, PUFA, n- 3 FA, and CLA was higher in the intervention period, but the intake of SFA was lower (p ≤0.05) | Outcomes and assessment methods:; Fasting blood lipids at start and end of each test period; [underlined: TC], mmol/L, Intervention; Control, Mean (SD); Intervention: 6.13 (0.97); Control: 6.23 (1.02); Between-group: P=NS; [underlined: LDL], mmol/L, Intervention; Control, Mean (SD); Intervention: 4.28 (0.92); Control: 4.34 (0.97); Between-group: P: NS; [underlined: HDL,] mmol/L, Intervention; Control, Mean (SD); Intervention: 1.14 (0.28); Control: 1.06 (0.23); Between-group: P≤0.05; [underlined: Triglycerides], mmol/L, Intervention; Control, Mean (SD); Intervention: 1.56 (0.98); Control: 1.84 (1.03); Between-group: P≤0.01 | Model adjustments:; None; Limitations:; - No information provided on randomization method; - Potential bias from missing data; Funding sources:; HERZGUT creamery
Drouin-Chartier, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/25604722) ^66^; RCT crossover, Canada; Baseline N=29 Analytic N=27 (Attrition: 7%); Participant characteristics at baseline: Postmenopausal women with abdominal obesity, ~57years, with BMI of ~31.9, 63% with metabolic syndrome, no CVD, no diabetes, no smoking, no hormone replacement therapy; Summary of findings:; Consumption of low fat milk in the context of a NCEP diet, compared to consuming a NCEP diet without milk, had significantly smaller decreases in total cholesterol, but had no significant effect on LDL and, HDL cholesterol and triglycerides in postmenopausal women with abdominal obesity. | Intervention and comparator:; - MILK diet: 3 portions 2% milk/day (20%E); diet consistent with National Cholesterol Education Program (NCEP) diet: 29%E fat, 10%SFA, CHO 55%, protein 17%; - NCEP no milk diet: comparable isocaloric diet (7d-cycle menus, calories and macronutrient composition) – added animal protein (mostly red meat and white egg powder), carbohydrate (mostly fruits) and lipids (mostly lard); [underlined: Duration of intervention:] 6 wk (4wk run-in, 6-8wk washout period); [underlined: Compliance:] Daily compliance sheets maintained by subjects indicated >98% compliance.; [underlined: Dietary intake for Intervention vs Control, Mean (SD), %E :]; SFA: 9.4 vs 9.8, P<0.05; MUFA: 12.0 vs 12.6, P=NS; PUFA: 4.8 vs 4.9, P=NS; Cholesterol: NS between groups; Other components of diet differed: carbohydrate, fat, calcium and vitamin D significantly higher in the MILK diet. | Outcomes and assessment methods:; Fasting blood lipids: start and end of each phase; [underlined: TC], mmol/L, Mean (SD) at post-intervention, % change; MILK: 5.6 (0.87) −2.6%; NCEP: 5.53 (0.76); −5.8%; MILK vs NCEP: P=0.01; [underlined: LDL], mmol/L, % change; MILK vs NCEP: P=0.42; [underlined: HDL], mmol/L, % change; MILK vs NCEP: P=0.29; [underlined: Triglycerides], mmol/L, % change; MILK vs NCEP: P=0.14 | Model adjustments:; Diet specific baseline values, changes in waist circumference; Limitations:; - No information provided on randomization method; Funding sources:; Canadian Institutes of Health Research, Dairy Farmers of Canada; Provigo/Loblaws
Engel, 2015 (https://pubmed.ncbi.nlm.nih.gov/26135349) ^68^; RCT crossover, Denmark; Baseline N=50 Analytic N=47 (Attrition: 6%); Participant characteristics at baseline: Healthy participants with normal BMI at ~40 years of age without diagnosis of current or previous CVD, diabetes or other severe chronic diseases; Summary of findings:; Intake of olive oil, compared to butter, was significantly associated with lower total cholesterol and lower LDL cholesterol. | Intervention and comparator:; - Butter (13.5 g fat; daily diet with butter baked in bread roll); - Refined olive oil (13.3 g; daily diet with olive oil baked in bread roll); [underlined: Duration of intervention:] 5 wk (run in: 2 wk; washout: 10 days); [underlined: Compliance:] 3-day dietary records (2 weekdays, 1 weekend); [underlined: Dietary intake for Intervention (butter) vs Control (olive oil), Mean (SD), g/day:]; SFA: 37.5 (15.7) vs 30.6 (13.3), P<0.0001; MUFA: NS; PUFA: NS; Cholesterol: NR; Other components of diet differed significantly: None | Outcomes and assessment methods:; Fasting blood lipids: measured in duplicate at baseline (before intervention) and after intervention; [underlined: TC], Mean (SD), mmol/L; Butter: 5.50 (0.98); Olive oil: 5.27 (0.95); P<0.05; [underlined: LDL], Mean (SD), mmol/L; Butter: 3.04 (0.86); Olive oil: 2.87 (0.86); P<0.05; [underlined: HDL], NS; [underlined: Triglycerides], NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - Insufficient washout period; - No preregistered statistical analysis plan; Funding sources:; Danish Dairy Research Foundation; Butter provided by Arla Foods, Denmark; Olive oil provided by AarhusKarlshamn, Denmark A/S.
Faghihnia, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/20713651) ^69^; RCT crossover, U.S.; Baseline N=NR Analytic N=63 (Attrition: NR); Participant characteristics at baseline: Participants (3% female) aged mean 48 years who had body weight <130% ideal, and total and LDL <95^th^ percentile for sex/age; Summary of findings:; Consuming a low-fat high carbohydrate diet for 4 weeks compared to a high-fat, low carbohydrate diet resulted in significantly decreased HDL- and LDL cholesterol, and increased triglycerides. There was no significant change in total cholesterol. | Intervention diets:; - High-fat, Low-carbohydrate (HFLC) diet:; - 15%E PRO, 40%E FAT,(13%E SFA, 11%E MUFA, 14%E PUFA, 3%E trans fat), 45%E CHO; - Low-fat, High-carbohydrate (LFHC) diet:; - 15%E PRO, 20%E FAT(5%E SFA, 10%E MUFA, 5%E PUFA, 2%E trans fat), 65%E CHO; - There were no differences in dietary cholesterol and the ratio of simple:complex carbohydrate (50:50) between the diets; [underlined: Duration of intervention:] 2 controlled feeding periods lasting 4 wk each, no washout period; [underlined: Compliance]: Good; <5% deviations; Dietary composition for HFLC and LFHC diets: see above | Outcomes and assessment methods:; Fasting blood lipids: Measured at baseline and after each 4 wk feeding period; Measures after HFLC, LFHC, and difference between interventions:; [underlined: TC,] mg/dL, Mean (SD); 192.0 (34.5), 187.0 (31.7), Difference: −5.0 (21.3), p=0.06; [underlined: LDL,] mg/dL, Mean (SD); 124.0 (31.3), 117.3 (30.7), Difference: −6.6 (22.0), p< 0.05; [underlined: HDL,] mg/dL, Mean (SD); 41.1 (7.7), 37.0 (7.4), Difference: −4.1 (3.8), p<0.0001; [underlined: Triglycerides,] mg/dL, Mean (SD); 134.0 (100.8), 165.4 (96.2), Difference: 31.4 (84.9), p<0.0001 | Model adjustments:; None; Limitations:; - No description of the randomization process; - No washout period between interventions; - No information about weight change during the intervention; - No description of baseline sample size, and whether any drop-out occurred after subjects were randomized; - No preregistered statistical analysis plan; Funding sources:; National Dairy Council and the Foundation Leducq.
Gilmore, 2011 (https://www.ncbi.nlm.nih.gov/pubmed/21525253) ^72^; RCT crossover, U.S.; Baseline N=30 Analytic N=27 (Attrition: 10%); Participant characteristics at baseline: Normocholesterolemic men ~36y with BMI ~27; Summary of findings:; Participants who consumed high MUFA patties (lower in SFA, higher in MUFA and oleic acid), compared to low MUFA patties, had greater positive change from baseline in HDL cholesterol. There were no differences in total blood cholesterol, LDL cholesterol and triglycerides. | Intervention and comparator:; - [underlined: Low MUFA] ground patties (5/wk): pasture-fed cattle (MUFA:SFA 0.70; Oleic acid: 10.1 g/114 g ground beef; LA: 0.55 g/114 g ground beef; ALA: 0.09 g/114 g ground beef); - [underlined: High MUFA] ground patties (5/wk): cattle fed grain-based diets (MUFA:SFA 1.10; Oleic acid: 13.3 g/114 g ground beef; LA: 0.56 g/114 g ground beef; ALA: 0.03 g/114g ground beef); [underlined: Duration of intervention:] 5 wk (4 wk washout); [underlined: Compliance:] 3-day diet record; [underlined: Dietary intake for Intervention (low MUFA) vs Control (high MUFA) at 5 wk, Mean (SD), g/day:]; Total fat: 97 (9) vs 97 (8), NS between groups; SFA: 39 (4) vs 36 (2), P=NR; Greater in low MUFA group; MUFA: 31 (4) vs 32 (3), P=NR; Greater in high MUFA group; Oleic acid: 27 (3) vs 27 (2), Higher in MUFA group; PUFA: 11 (1) vs 12 (2), P=NR; LA: 8 (1) vs 9 (2), NS between groups; ALA: 1 (1) vs 1 (1), NS between groups; Cholesterol: 325 (44) vs 325 (43), NS between groups; Other components of diet differed significantly: None | Outcomes and assessment methods:; Fasting blood lipids at baseline and 5 wk follow-up; [underlined: TC], mmol/L, Mean (SD); Change from baseline:; Low MUFA vs High MUFA: NS; [underlined: LDL], mmol/L, Mean (SD); Change from baseline:; Low MUFA vs High MUFA: NS; [underlined: HDL], mmol/L, Mean (SD); Change from baseline:; Low MUFA vs High MUFA: P<0.05 (high MUFA patties had greater positive change from baseline, compared to low MUFA patties); [underlined: Triglycerides], mmol/L, Mean (SD); Change from baseline:; Low MUFA vs High MUFA: NS | Model adjustments:; None; Limitations:; - No information on randomization of allocation sequence; - No information on compliance; - No preregistered statistical analysis plan; Funding sources:; Beef Checkoff through National Cattlemen’s Beef Association
Harris, 2017 (https://www.ncbi.nlm.nih.gov/pubmed/28277823) ^76^; RCT crossover, U.S.; Baseline N=14 Analytic N=12 (Attrition: 14%); Participant characteristics at baseline: Postmenopausal women (mean age 59 y) with BMI ~26 and normal fasting lipids at baseline; Summary of findings:; Consumption of virgin coconut oil for 4 weeks resulted in significant increases in total blood cholesterol, LDL, and HDL cholesterol; whereas consumption of safflower oil resulted in significant decreases in total blood and LDL cholesterol. The between-group difference in change was significant for total blood, LDL, and HDL cholesterol. There were no significant differences between groups in triglycerides. | Intervention and comparator:; - Virgin coconut oil (VCO) (30 mL/d): 97% SFA, 3% Oleic acid, <1% LA; - Safflower oil (SO) (30 mL/d): 6% SFA, 80% Oleic acid, 13% LA; - Participants instructed to add test oils to already-prepared foods as toppings or dressings (not to cook with them).; - Participants instructed to maintain current diet; [underlined: Duration of intervention:] 4 wk each dietary period (washout: 4 wk); [underlined: Compliance:] 8 days/month food records (total of 28 day food journals); “high rate” reported; [underlined: Dietary intake for Intervention vs Control, Mean (SD), g/day:]; SFA: NR; MUFA: NR; PUFA: NR; Cholesterol: NR; Other components of diet differed significantly: Protein: VCO (before; after): 83 (62); 96 (62); SO: 69 (15); 68 (18), P≤0.05 | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 wk follow-up; Difference in change between groups; [underlined: TC], mg/dL, Mean (SD); Before; after values plan; VCO: 219.6 (32.6), 237.8 (24.1), Change: +18.20; SO: 222.8 (25.6), 219.3 (22.8), Change: −3.50; VCO vs SO (change): P≤0.05; [underlined: LDL], mg/dL, Mean (SD); Before; after values; VCO: 124.0 (24.7), 137.5 (27.2), Change: +13.50; SO: 130.7 (25.6), 126.8 (25.7), Change: −3.90; VCO vs SO (change): P≤0.05; [underlined: HDL], mg/dL, Mean (SD); Before; after values; VCO: 63.9 (16.2), 70.5 (18.8), Change: +6.60; SO: 63.2 (14.7), 62.9 (14.5), Change: −0.30; VCO vs SO (change): P≤0.05; [underlined: Triglycerides], mg/dL, Mean (SD); VCO vs SO (change): NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - No preregistered statistical analysis; Funding sources:; University of Colorado, Colorado Springs’ Committee on Creative and Research WorkSeed Grant Program; Tropical Traditions donated oils
Hyde, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/31217353) ^77^; RCT crossover, U.S.; Baseline N=21 Analytic N=16 (Attrition: 24%); Participant characteristics at baseline: Participants (38% female) aged mean 41 years who were obese (BMI) diagnosed with metabolic syndrome; Summary of findings:; After 4wk, there were no significant group differences in LDL cholesterol. All subjects combined and men had significantly decreased HDL cholesterol and decreased triglycerides after the HC diet. | Intervention diets:; - Low Carbohydrate (LC) diet: 20%E PRO, 74%E FAT, 6%E CHO, 100 g/d SFA; - Moderate Carbohydrate (MC) diet: 20%E PRO, 48%E FAT, 32%E CHO, 70 g/d SFA; - High Carbohydrate (HC) diet: 20%E PRO, 23%E FAT, 57%E CHO, 40 g/d SFA; - Controlled feeding trial; - Isocaloric diets; [underlined: Duration of intervention:] 2 wk run-in on a standard American diet, followed by 3 controlled feeding periods lasting 4 wk each, with 2 wk washout period in between; [underlined: Compliance]: measured daily; compliance NR; [underlined: Dietary intake for Intervention diets (HC, MC, LC), Mean (Range), g (mg cholesterol):]; SFA: 40 (28–51), 70 (48–89), 100 (69–127); MUFA: 21 (15–27), 54 (37–69), 86 (59–110); PUFA: 6 (5–8), 21 (14–26), 35 (24–45); Cholesterol: 334 (231–425), 503 (347–639), 1,015 (701–1291); Other components of diet differed significantly:; CHO: 420 (290–534), 234 (161–297), 45 (31–58); PRO: 144 (100–184), 146 (101–185), 150 (103–190); FAT: 77 (53–97), 159 (110–202), 242 (167–307) | Outcomes and assessment methods:; Fasting blood lipids: Measured at baseline and after each 4 wk feeding period; Measures at baseline, and after LC, MC, HC (a vs b vs c denotes significant between group differences):; Comparing difference in change; [underlined: LDL], mg/dL; All: NS; Men: NS; Women: NS; [underlined: HDL], mg/dL; All: 37 (9), 40 (11)b, 35 (9)c, 34 (8)c, p=0.009; Men: 33 (9), 35 (9)b, 32 (7)b, 30 (7)c, p=0.027; Women: NS; [underlined: Triglycerides], mg/dL; All: 177 (58), 120 (38)b, 189 (103)c, 199 (70)c, P=0.006; Men: 188 (57), 114 (32)b, 181 (85)bc, 217 (83)c, P=0.019; Women: NS | Model adjustments:; None; Limitations:; - No description of the randomization process; - Potential bias from missing data; - No preregistered statistical analysis plan; Funding sources:; National Dairy Council and the Dutch Dairy Association
Intorre, 2011 (https://www.ncbi.nlm.nih.gov/pubmed/21591986) ^79^; RCT crossover, Italy; Baseline N=30, Analytic N=30 (Attrition: 0%); Participant characteristics at baseline: Normolipidemic adults (~66% female) 20-40y of age and with mean BMI of ~23.; Summary of findings:; In participants self-selecting their diet, consumption of cheese lower in SFA, and higher in MUFA and PUFA, for 4 weeks did not change fasting blood lipids compared to consumption of conventional cheese higher in SFA and lower in MUFA and PUFA. | Intervention and comparator diets:; - Experimental cheese lower in SFA and higher in MUFA and PUFA, three 50g serving/wk; - Sources: From cows fed diet with added linseed oil; - Control cheese higher in SFA and lower in MUFA and PUFA, three 50g serving/wk; - Sources: From cows fed diet without added linseed oil; [underlined: Duration of intervention:] 4 wk (preceded by 2 wk run in; 1mo washout between interventions); [underlined: Compliance:] Monitored via food records and 24 hour recalls; Cheese was consumed “as indicated”; [underlined: Total dietary intake for Control cheese vs Experimental cheese, Mean (SD), %E:]; SFA: 12.0 (2.5) vs 12.7 (2.9), P=NS; MUFA: 18.4 (4.5) vs 18.8 (4.0), P=NS; PUFA: 5.3 (0.9) vs 5.2 (1.0), P=NS; Cholesterol: NR; Other components of diet differed significantly: None | Outcomes and assessment methods:; [underlined: Changes in Fasting blood lipids:]; Measured at beginning and end of 4wk period; [underlined: TC], mmol/L, Mean (SD); Experimental vs Control: P=NS; [underlined: LDL], mmol/L, Mean (SD); Experimental vs Control: P=NS; [underlined: HDL], mmol/L, Mean (SD); Experimental vs Control: P=NS; [underlined: Triglycerides], mmol/L, Mean (SD); Experimental vs Control: P=NS | Model adjustments:; None; Limitations:; - No information on method of randomization; - No preregistered statistical analysis plan; Funding sources:; TRUEFOOD project (European Commission under the 6^th^ Framework Programme for RTD)
Isherwood, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/20196970) ^80^; RCT crossover, U.K.; Baseline N=25 Analytic N=23 (Attrition: 8%); Participant characteristics at baseline: Normo-lipidemic men aged ~41 with BMI ~26, free of dietary supplements; Summary of findings:; Consumption of 8 ounces of prawns (which increased dietary cholesterol), daily for 4 weeks, compared to 8 ounces of fish sticks, did not significantly change total cholesterol, LDL, HDL cholesterol or triglycerides. | Intervention and comparator:; - 225 g/day (~8 oz) cold water prawns daily: dietary cholesterol 295 mg, EPA+DHA: 0.6-0.7 g; - 225 g/day (~8 oz) of fish (‘crab’) sticks: traces of dietary cholesterol and n-3 PUFA; [underlined: Duration of intervention:] 4 wk each diet (washout 4 wk); [underlined: Compliance:] 3-day diet diaries; participants were compliant with study protocol; [underlined: Dietary intake for Intervention vs Control, Mean (SD), g/day:]; SFA: 19 (5) vs 21 (10); MUFA: 22 (6) vs 22 (10); PUFA: 14 (8) vs 11 (7); Cholesterol (mg/d): 794 (186) vs 275 (92), P<0.001; Other components of diet differed significantly: None | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 wk follow-up; Difference in change; [underlined: TC], mmol/L, Mean (SD); Prawn vs control: NS; [underlined: LDL], mmol/L, Mean (SD); Prawn vs control: NS; [underlined: HDL], mmol/L, Mean (SD); Prawn vs control: NS; [underlined: Triglycerides], mmol/L, Mean (SD); Prawn vs control: NS | Model adjustments:; None; Limitations:; - No preregistered statistical analysis plan; Funding sources:; European Fisheries Fund and Sea Fish Industry Authority
Jones, 2014 (https://www.ncbi.nlm.nih.gov/pubmed/24829493) ^83^; RCT crossover, COMIT I, U.S. and Canada; Baseline N=170 Analytic N=130 (Attrition: 24%); Participant characteristics at baseline: Nonsmoking adults ~46y of age with at least one cardiovascular risk factor and who were, on average, overweight (BMI, 29.8).; Summary of findings:; Among adults with at least one cardiovascular risk factor, consuming oils with different FA profiles had different effects on blood lipids after 4 weeks. Corn-safflower (high in LA), flax-safflower (high in ALA), and canola-oleic (high in oleic acid) reduced total blood and LDL cholesterol compared to canola-DHA (high in DHA). Canola-DHA increased HDL cholesterol and decreased triglycerides compared to canola, corn-safflower, flax-safflower, and canola-oleic. | Intervention and comparator:; - Canola oil (59% oleic acid, 20% LA, 10% ALA); - Canola-DHA oil (63% oleic acid, 6% DHA); - Corn-Safflower oil (18% oleic acid, [underlined: 69% LA]); - Canola-Oleic oil (72% oleic acid, 15% LA); - Flax-Safflower oil (18% oleic acid, 38% LA, 32% ALA); [underlined: Fatty acid composition of Canola, Canola DHA, CornSaff, FlaxSaff, and Canola Oleic, (% fat):]; SFA: 7.3 vs 9.0 vs 7.9 vs 8.1 vs 6.9; MUFA: 60.3 vs 64.7 vs 17.7 vs 17.9 vs 73.2; Oleic acid: 58.6 vs 63.2 vs 17.6 vs 17.9 vs 71.5; PUFA: 29.3 vs 23.1 vs 69.6 vs 69.5 vs 17.0; LA: 19.5 vs 12.7 vs 69.3 vs 37.5 vs 14.7; ALA: 9.8 vs 2.0 vs 0.3 vs 32.0 vs 2.3; EPA: 0 vs 0.2 vs 0 vs 0 vs 0; DPA: 0 vs 2.4 vs 0 vs 0 vs 0; DHA: 0 vs 5.8 vs 0 vs 0 vs 0; - All diets weight-maintaining with fixed macronutrient composition: 15% protein, 50% CHO, 35% fat; - All food provided by study; [underlined: Duration of intervention:] 4 wk each dietary period (4 wk wash-out); [underlined: Compliance:] Assessed by study coordinators by completion of meals provided under supervision and by presence of food not consumed in returned meal bags for off-site consumption; [underlined: Diet composition for Canola vs Canola-DHA vs Corn-Safflower vs Canola-Oleic vs Flax-Safflower, Mean, %E:]; SFA: 6.6 vs 6.9 vs 6.7 vs 6.5 vs 6.8; MUFA: 17.6 vs 17.8 vs 9.5 vs 19.3 vs 9.6; PUFA: 9.1 vs 8.0 vs 16.3 vs 6.9 vs 16.3; Cholesterol: NR; Other components of diet differed significantly: None | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at start of dietary phase and 4 wk. Different letters indicate different at P<0.05; [underlined: TC], Mean (SE); At 4 wk, mmol/L:; Canola: 4.81 (0.14) ab; Canola-DHA: 4.87 (0.14) a; Corn-Safflower: 4.74 (0.14) bc; Flax-Safflower: 4.69 (0.14) c; Canola-Oleic: 4.77 (0.14) bc; Percentage change, %:; Canola: −8.5 (2.5) a; Canola-DHA: −7.4 (2.5) a; Corn-Safflower: −11.7 (2.5) b; Flax-Safflower: −11.4 (2.5) b; Canola-Oleic: −9.4 (2.5) ab; [underlined: LDL], Mean (SE); At 4 wk, mmol/L:; Canola: 2.91 (0.08) b; Canola-DHA: 3.02 (0.08) a; Corn-Safflower: 2.85 (0.08) b; Flax-Safflower: 2.84 (0.08) b; Canola-Oleic: 2.86 (0.08) b; Percentage change, %:; Canola: −11.3 (2.8) ab; Canola-DHA: −7.0 (2.8) b; Corn-Safflower: −15.4 (2.8) a; Flax-Safflower: −12.9 (2.8) a; Canola-Oleic: −12.5 (2.8) a; [underlined: HDL], Mean (SE); At 4 wk, mmol/L:; Canola: 1.20 (0.02) b; Canola-DHA: 1.30 (0.02) a; Corn-Safflower: 1.20 (0.02) b; Flax-Safflower: 1.17 (0.02) b; Canola-Oleic: 1.18 (0.02) b; Percentage change, %:; Canola: −4.2 (1.8) a; Canola-DHA: +3.5 (1.8) b; Corn-Safflower: −4.4 (1.8) a; Flax-Safflower: −6.8 (1.8) a; Canola-Oleic: −5.0 (1.8) a; [underlined: Triglycerides], Mean (SE); At 4 wk, mmol/L:; Canola: 1.60 (0.10) a; Canola-DHA: 1.25 (0.10) b; Corn-Safflower: 1.56 (0.10) a; Flax-Safflower: 1.56 (0.10) a; Canola-Oleic: 1.64 (0.10) a; Percentage change, %:; Canola, Corn-Safflower, Flax-Safflower, Canola-Oleic: All NR, a; Canola-DHA: −20.7 (3.8) b | Model adjustments:; Age, sex, center (random effect), last treatment (random effect); Limitations:; - No information on whether analyses were robust to missing data; - No preregistered statistical analysis plan; Funding sources:; Canola Council of Canada; Flax Council of Canada; Agriculture and Agri Food Canada; Dow Agrosciences; Canada Research Chairs; Western Grains Research Foundation; National Center for Research Resources; National Center for Advancing Translational Sciences
Karupaiah, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/27535127) ^85^; RCT crossover, Malaysia; Baseline N=34 Analytic N=34 (Attrition: 0%); Participant characteristics at baseline: Young adults (53% female), ~23y of age, with BMI ~25.; Summary of findings:; In young adults, consumption of soybean oil based mayo for 4 weeks (which increased n-6 PUFA intake and decreased SFA and MUFA intake) significantly reduced total blood and LDL cholesterol relative to a palm olein based mayo. The soybean oil based mayo also decreased HDL cholesterol compared to the palm olein based mayo, and had no between-group effect on triglycerides | Intervention and comparator:; - Mayonnaise (~20g/d) made with soybean oil (high LA); - Mayonnaise (~20g/d) made with palm olein; - All meals provided by the study (fixed total fat and cholesterol content); [underlined: Fatty acid composition for Soybean vs Palm olein-mayo; duplicated total diet (%):]; SFA: 14.0 vs 41.7; 35.1 vs 41.9, P<0.05; MUFA: 24.5 vs 45.3; 38.5 vs 42.8, P<0.05; PUFA: 58.7 vs 12.6; 25.7 vs 14.4, P<0.05; Palmitic acid: 10.4 vs 37.7; 28.0 vs 34.6, P<0.05; Stearic acid: NS; Oleic acid: 24.3 vs 45.1; 37.5 vs 41.8, P<0.05; LA: 53.1 vs 12.3; 23.4 vs 13.0, P<0.05; C18:3n6: Mayo: not detected; 0.18 vs 0.04, P<0.05; ALA: 5.6 vs 0.3; 1.05 vs 0.77, P=NS; Total n-6: 53.1 vs 12.3; 24.0 vs 13.2, P<0.05; Total n-3: 5.6 vs 0.3; 1.05 vs 0.77, P<0.05; [underlined: Duration of intervention:] 4 wk each dietary period (Wash-out: 2 wk); [underlined: Compliance:] Monitored via meal time attendance records, 3, 24 hour recalls per crossover period; [underlined: Total diet for Soybean Oil Mayonnaise vs Palm Olein Mayonnaise, Mean (SD), % of FA:]; SFA: 35.1 (2.8) vs 41.9 (1.3), P<0.05; MUFA: 38.5 (1.3) vs 42.8 (1.8), P<0.05; PUFA: 25.7 (3.6) vs 14.4 (0.9), P<0.05; n-6 PUFA: 24.0 (3.7) vs 13.2 (1.0), P<0.05; n-3 PUFA: 1.05 (0.41) vs 0.77 (0.87), P=NS; Cholesterol: NR; Other components of diet differed significantly: None | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline and in duplicate at 4 wk.; Between group differences at 4 wk; [underlined: TC], mmol/L, Mean (SD); Baseline: 5.20 (0.56); Soybean Oil: 4.80 (0.65); Palm Olein: 5.06 (0.61); Between group differences P=0.001; [underlined: LDL], mmol/L, Mean (SD); Baseline: 3.37 (0.52); Soybean Oil: 3.05 (0.57); Palm Olein: 3.22 (0.57); Between group differences P=0.016; [underlined: HDL], mmol/L, Mean (SD); Baseline: 1.39 (0.27); Soybean Oil: 1.21 (0.27); Palm Olein: 1.34 (0.30); Between group differences P<0.001; [underlined: Triglycerides], mmol/L, Mean (SD); Soybean Oil vs Palm Olein: P=NS | Model adjustments:; Change in body weight; Limitations:; - No information provided on randomization method; - No preregistered statistical analysis plan; Funding sources:; Kewpie Corporation, Japan
Katz, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/23756586) ^86^; RCT crossover, U.S.; Baseline N=46 Analytic N=40 (Attrition: 13%); Participant characteristics at baseline: Nonsmoking adults (~61% female) ~57y of age with overweight or obesity, high waist circumference, and one or more additional risk factors for metabolic syndrome; Summary of findings:; In adults with overweight or obesity and at risk for metabolic syndrome, consuming a walnut enriched diet for 8 weeks (which increased PUFA intake) did not significantly change blood lipids relative to a diet without walnuts. | Intervention and comparator diets:; - Walnut enriched ad libitum diet, 56g/d daily; Counseled to substitute walnuts for other foods in diet to keep weight stable; - Sources: unroasted English walnuts; - Control: Ad libitum diet without walnuts; - Sources: NA; [underlined: Duration of intervention:] 8 wk (4 wk run in; 4 wk washout); [underlined: Compliance:] Assessed via diet records and consumption log sheets; 1 participant dropped out due to inability to comply with protocol; [underlined: Dietary intake during Walnut diet vs Control diet, Mean (SD), %E:]; SFA: 11.8 (3.5) vs 11.6 (3.6), P=NS; MUFA: 10.8 (3.0) vs 10.7 (3.2), P<0.01; PUFA: 13.2 (6.0) vs 6.0 (2.8), P<0.01; n-3 PUFA: 2.1 (0.8) vs 0.6 (1.1), P<0.01; n-6 PUFA: 10.7 (5.1) vs 4.8 (2.5), P<0.01; Cholesterol (mg/d): 297.1 (176.5) vs 321.9 (172.0), P=NS; Other components of diet differed significantly: Total fat (higher in walnut), protein and CHO (lower in walnut). | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline and 8 wk; Comparing change from baseline between groups; [underlined: TC], mg/dL; Walnut vs Control: P=NS; [underlined: LDL], mg/dL; Walnut vs Control: P=NS; [underlined: HDL], mg/dL; Walnut vs Control: P=NS; [underlined: Triglycerides], mg/dL; Walnut vs Control: P=NS | Model adjustments:; Age, race, BMI, hypertensive status, dyslipidemia, treatment sequence; Limitations:; - No information on randomization of allocation sequence; - No information on whether results were robust to missing data; - Trial register does not contain sufficient information to assess selection of reported results; Funding sources:; California Walnut Commission
Kawakami, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/25896182) ^87^; RCT crossover, Japan; Baseline N=21 Analytic N=15 (Attrition: 29%); Participant characteristics at baseline: Participants (0% female) aged ~45 with BMI ~25; Summary of findings:; Consumption of flaxseed oil (higher in ALA), compared to corn oil, resulted in significant between group differences in total blood, LDL, and HDL cholesterol. There were no significant differences in triglycerides between groups. | Intervention and comparator:; - Flaxseed oil (high ALA) (10 g/day); - Corn oil (10 g/day); - Participants instructed to consume test oils (10 g/d) using a spoon once daily with dinner; [underlined: Fatty acid composition of flaxseed oil and corn oil (g/100g):]; Palmitic acid: 5.2 vs 12.0; Stearic: 3.8 vs 2.0; Oleic: 18.9 vs 29.1; LA: 16.2 vs [underlined: 54.5]; ALA: [underlined: 54.9] vs 0.9; AA: 0.2 vs 0.5; n6:n3 ratio: 0.3 vs 60.6; [underlined: Duration of intervention:] 12 wk (washout: 8 wk); [underlined: Compliance:] food diary every 2 wk and remaining volumes of oil; all subjects consumed >97% of oil; [underlined: Dietary intake for flaxseed vs corn oil at 12wk, Mean (SD), units/day:]; Total fat (g): 64.1 (4.1) vs 71.4 (3.2), P=NS; ALA (mg): 6,032.0 (140.0) vs 1,606.0 (136.0), P<0.05; EPA (mg): 225 (75) vs 153 (59), P=NS; DHA (mg): 383 (109) vs 288 (85), P=NS; LA (mg): 8,106 (775) vs 15,675 (688), P<0.05; n6:n3 ratio: 1.2 (0.1) vs 8.3 (0.8), P<0.05; Other components of diet differed significantly: alpha-tocopherol: 8.1 (0.6) vs 5.4 (0.5), P<0.05 | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 and 12 wk follow-up; [underlined: TC], mg/dL, Mean (SD); Flaxseed oil: 202.3 (7.3); Corn oil: 216.9 (7.7); Between group difference at 12wk: P<0.05; [underlined: LDL], mg/dL, Mean (SD); Flaxseed oil: 127.7 (7.2); Corn oil: 137.9 (7.7); Between group difference at 12wk: P<0.05; [underlined: HDL], mg/dL, Mean (SD); Flaxseed oil: 49.2 (2.7); Corn oil: 54.9 (3.0); Between group difference at 12wk: P<0.05; [underlined: Triglycerides], mmol/L, Mean (SD); Flaxseed oil vs corn oil: NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - No information on whether missing data was different between groups; - No preregistered statistical analysis plan; Funding sources:; Ministry of Agriculture, Forestry, and Fisheries; Sadamitsu Food Industry Limited
Kontogianni, 2013 (https://www.ncbi.nlm.nih.gov/pubmed/23347535) ^90^; RCT crossover, Greece; Baseline N= 53 Analytic N=37 (Attrition: 30%); Participant characteristics at baseline: Healthy, normal weight adults (78% female) mean 25.6y and 22 BMI, free of CHD, diabetes, MedDietScore 34; Summary of findings:; Diets enriched with flaxseed oil versus olive oil did not significantly change blood total, LDL and HDL cholesterol and triglycerides in adults who traditionally use olive oil as the main dietary oil. | Intervention and comparator:; - Flaxseed oil (15mL/d or 13.8g); - Olive oil (extra virgin) (15mL/d); - Diets enriched: Participants instructed to incorporate oils into their daily dietary intake without substituting any of their current oil intakes; [underlined: Fatty acid composition of flaxseed oil vs olive oil (g/day):]; Oleic acid: 3 vs 11.3; ALA: 8 vs 0.13; [underlined: Duration of intervention:] 6 wk each diet (6 wk washout); [underlined: Compliance]: 7 non–compliant with flaxseed oil (change in erythrocyte membrane ALA concentration < 0.06%E); Mean change: 0.18 (range −0.04-.043); [underlined: Dietary intake for Flaxseed vs Olive oil, Mean (SD):]; SFA (%E): NS; MUFA (%E): NS; PUFA (%E): 8.4 (1.9) vs 6.0 (5.9), P<0.001; n-3/n-6 FA ratio: 1.4 (1.2) vs 8.3 (3.5), P<0.001; ALA (g/d): 8.7 (2.2) vs 0.8 (0.3), P<0.001; EPA (g/d): 0.05 (0.09) vs 0.08 (0.12), P=0.02; DHA (g/d): NS; No differences observed in macronutrients, fiber and alcohol. | Outcomes and assessment methods:; Fasting blood lipids assessed the first and last day of each intervention; Levels after dietary intervention; [underlined: TC], flaxseed vs olive oil, P=NS; [underlined: LDL], flaxseed vs olive oil, P=NS; [underlined: HDL], flaxseed vs olive oil, P=NS; [underlined: Triglycerides], flaxseed vs olive oil, P=NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - Proportion of missing outcome data not balanced; - No preregistered statistical analysis plan; Funding sources:; NR, (Minerva S.A supplied olive oil)
Kovell, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/31447226) ^91^; RCT crossover, OmniHeart, U.S.; Baseline=191 Analytic N= 164 (Attrition: 14%); Participant characteristics at baseline: ~53.6 y, 45% female, BMI ~30.2, 55% African American, 100% high BP or HTN, no HTN or hyperlipidemia medication, no CVD, no diabetes; Summary of findings:; Replacement of 10% carbohydrate by unsaturated fat for 6 weeks did not significantly affect blood LDL cholesterol levels in healthy adults with pre- or stage 1 hypertension. | Intervention diet:; - Carbohydrate-rich diet (CARB): 58% carbohydrate, 15% protein, 27% fat, 6% SFA, 13% MUFA, 8%PUFA); - Protein-rich diet (PROT): 10% CHO replaced by protein (48% CHO, 25% protein, 27% fat, 6% SFA, 13% MUFA, 8%PUFA); - Unsaturated fat-rich diet (UNSAT): 10% CHO replaced by unsaturated fat (48% CHO, 15% protein, 37% fat, 6% SFA, 21% MUFA, 10%PUFA); - All diet interventions were weight maintenance, low in saturated fat, cholesterol, and sodium.; - Meals prepared in a research kitchen.; [underlined: Duration of intervention:] 6 wk (2-4 wk washout); [underlined: Compliance:] 95% of trial person days, i.e. complete consumption of all study foods without any non-study foods; [underlined: Dietary intake for CARB vs PROT vs UNSAT, Mean (SD), (%):]; SFA: 6 vs 6 vs 6; MUFA: 13 vs 13 vs 21; PUFA: 8 vs 8 vs 10; Cholesterol: NR (NS); Other components of diet differed significantly: CHO: 58 vs 48 vs 48 | Outcomes and assessment methods:; Fasting blood lipids: At baseline and after each feeding period.; Comparisons between groups at end of each feeding period; [underlined: LDL], mg/dl, Mean change from baseline; UNSAT vs CARB: P=0.22 | Model adjustments:; None; Limitations:; - Attrition >10%; Funding sources:; NIH/NHLBI
[underlined: Liu, 2018] ^94^; RCT crossover, COMIT, Canada and U.S.; Baseline N=130 Analytic N= 101 (Attrition: 25%); Participant characteristics at baseline: Adults (50% female) with or at risk for metabolic syndrome, mean age ~50 y, with a BMI of ~29.4 and central obesity; Summary of findings:; After 4 weeks, five oil interventions (canola, canola oleic, and canola DHA oils, corn and safflower oil blend, and fax and safflower oil blend), which were low in SFAs and high in MUFAs or PUFAs, significantly decreased total- and LDL cholesterol and triglyceride concentrations from baseline in adults with or at risk for metabolic syndrome. Canola DHA had a significantly greater effect on increasing HDL cholesterol and decreasing triglycerides than the other four oil types. | Intervention and comparators:; - [underlined: Conventional Canola oil] (3.8 g ALA); - [underlined: Canola Oleic:] High oleic acid–canola oil (1.2 g ALA); - [underlined: Canola DHA:] DHA-enriched high oleic acid–canola oil (1.2 g ALA and 3.6 g DHA); - Corn oil and safflower oil blend (Corn/Saff); - Flax oil and safflower oil blend (Flax/Saff) (6.9 g ALA); - Participants consumed 2 smoothies per day (each containing treatment oil) as part of an isocaloric diet.; - Treatment oils provided ~18% of total fat energy per day; for a 3,000kcal diet, 60 g treatment oil/day was incorporated into smoothies.; [underlined: Fatty acid composition of Canola vs Canola Oleic vs Canola DHA, CornSaff and FlaxSaff (% of total fat):]; SFA: 7.2 vs 6.5 vs 8.6 vs 7.9 vs 8.1; MUFA: 62.8 vs 72.0 vs 63.8 vs 17.7 vs 17.9; PUFA: 29.5 vs 17.0 vs 23.3 vs 69.6 vs 69.4; ALA: 9.8 vs 2.3 vs 2.2 vs <1.0 vs 32.0; DHA: 0 vs 0 vs 5.8 vs 0 vs 0; LA: 19.5 vs 14.7 vs 12.7 vs 69.3 vs 37.5; All food was provided to participants (3 meals and a snack daily) during the feeding period.; All diets (%E): 50% CHO, 15% Protein, 35% fat (18% from treatment oil); [underlined: Duration of intervention:] 4 wk each treatment period (2-4 wk washout); [underlined: Compliance]: NR; assessed via based remaining amounts of treatment shakes in pre-packaged food packs, weekly diet questionnaires and change in serum DHA; [underlined: Dietary intake for all groups, Mean (SD):]; SFA: NR; MUFA: NR; PUFA: NR; Cholesterol: NR | Outcomes and assessment methods:; Fasting blood lipids: assessed at day 1 and days 29 and 30 (endpoint) for each treatment period.; Changes in lipid values from baseline in response to treatment oils; [underlined: TC], mmol/L, Mean (SEM); Canola oil: −0.58 (0.051); Canola Oleic: −0.61 (0.06); Canola DHA: −0.54 (0.06); Corn/Saff: −0.62 (0.06); Flax/Saff: −0.68 (0.04); All differences from baseline P<0.05; Group differences: Canola DHA vs Corn/Saff; Flax/Saff P<0.05; [underlined: LDL], mmol/L, Mean (SEM) Canola oil: −0.54 (0.05); Canola Oleic: −0.55 (0.05); Canola DHA: −0.58 (0.054); Corn/Saff: −0.59 (0.05); Flax/Saff: −0.60 (0.048); All differences from baseline P<0.05; NS differences between groups; [underlined: HDL], mmol/L, Mean (SEM); Canola oil: −0.04 (0.02); Canola Oleic: −0.02 (0.02); Canola DHA: +0.07 (0.02); Corn/Saff: −0.01 (0.02) - NS; Flax/Saff: −0.04 (0.02); All differences from baseline P<0.05 except for Corn/Saff; Group differences: Canola DHA > Corn/Saff; Flax/Saff; Canola oil; Canola Oleic, P<0.05; [underlined: Triglycerides], mmol/L, Mean (SEM); Canola oil: −0.14 (0.05); Canola Oleic: −0.07 (0.04); Canola DHA: −0.50 (0.04); Corn/Saff: −0.19 (0.05); Flax/Saff: −0.17 (0.04); All differences from baseline P<0.05; Group differences: Canola DHA > Corn/Saff; Flax/Saff; Canola oil; Canola Oleic P<0.05 | Model adjustments:; Diet, visit, age, gender, obesity status, center; Limitations:; - Some concern about deviations from intended interventions due to compliance NR; Funding sources:; Agriculture and Agri Food Canada; Canola Council of Canada, Dow Agrosciences and Flax Council of Canada; National Center for Research Resources; NIH Grant
McDaniel, 2013 (https://www.ncbi.nlm.nih.gov/pubmed/23602247) ^97^; RCT crossover, U.S.; Baseline N=14 Analytic N=10 (Attrition: 29%); Participant characteristics at baseline: Healthy males ~34y with BMI ~25; Summary of findings:; Participants who consumed beef or bison (12 ounces for 6 days per week for 7 weeks had no differences in total blood, LDL, or HDL cholesterol or triglycerides. | Intervention and comparator:; - 340 g (12 oz) beef (6 days/wk); - 340 g (12 oz) bison (6 days/wk); - Beef vs Bison roasts:; - SFA (% fat): 41 (4) vs 38 (3), P>0.05; - MUFA (% fat): 50 (2) vs 45 (4), P>0.05; - PUFA (% fat): 7 (2) vs 15 (3), P<0.05; - N-6 PUFA (% fat): 7 (2) vs 14 (3), P<0.05; - N-3 PUFA (% fat): 0.4 (0.2) vs 0.9 (0.1), P<0.05; - N-6/N-3 ratio: 17 (5) vs 16 (2), P>0.05; [underlined: Duration of intervention:] 7 wk (washout 4 wk); [underlined: Compliance:] daily compliance checklist; participants had “excellent compliance”; [underlined: Dietary intake for Intervention vs Control, Mean (SD), g/day:]; SFA: Significant increase in beef but not bison, P<0.05; MUFA: NR; PUFA: NR; Cholesterol: NR; Other components of diet differed significantly: Protein intake increased with bison but not beef consumption | Outcomes and assessment methods:; Fasting blood lipids at baseline and 7 wk follow-up; [underlined: TC], mmol/L, Mean (SD); Relative change: Beef vs Bison: NS; [underlined: LDL], mmol/L, Mean (SD); Relative change: Beef vs Bison: NS; [underlined: HDL], mmol/L, Mean (SD); Relative change: Beef vs Bison: NS; [underlined: Triglycerides], mmol/L, Mean (SD); Relative change: Beef vs Bison: NS | Model adjustments:; None; Limitations:; - No information on randomization of allocation sequence; - No preregistered statistical analysis plan; Funding sources:; National Buffalo Foundation; NIH; Veterans Affairs
McKay, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/29534487) ^98^; RCT crossover, U.S.; Baseline N=26 Analytic N=26 (Attrition: 0%); Participant characteristics at baseline: Nonsmoking adults (19% female) with overweight or obesity, ~58y (males) or ~67y (females) of age; Summary of findings:; Consumption of a diet rich in pecans for 4 weeks (which increase MUFA intake at the expense of SFA) did not significantly change blood lipids relative to a control diet without pecans except in some subgroups. | Intervention and comparator:; - Diet enriched in pecans (~15%E; 42.5 grams or 1.5 ounces daily); - Sources: Pecans; - Control: Diet resembling typical American diet; - Sources: NA; - All meals/snacks provided. Participants picked up meals and dropped off empty containers and unused food twice a week; [underlined: Duration of intervention:] 4 wk (2 wk run-in, 2 wk washout); [underlined: Compliance:] Monitored by study dietitian, NR; Confirmed via RBC FAs of primary MUFAs in pecans; [underlined: Estimated study diet composition for Pecan vs Control, %E:]; SFA: 9.1 vs 13.6; MUFA: 14.8 vs 10.8; PUFA: 8.6 vs 8.4; Cholesterol (mg): 249 vs 256; Other components of diet differed significantly: None | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline and 4 wk; Tested between group differences in change; [underlined: TC], mg/dL, Mean change (SE) Pecan vs Control: P=NS; When stratified by LDL cholesterol (<130mg/dL vs ≥130mg/dL):; <130mg/dL: Pecan 4.15 vs Control 17.20, Difference −13.05, P=0.035; ≥130mg/dL: P=NS; [underlined: LDL], mg/dL, Mean change (SE) Pecan vs Control: P=NS; When stratified by blood glucose (≤100mg/dL vs >100mg/dL): ≤100mg/dL: P=NS; >100mg/dL: Pecan −7.19 vs Control 8.39, Difference −15.58, P=0.006; [underlined: HDL], mg/dL; Pecan vs Control: P=NS; [underlined: Triglycerides], mg/dL; Pecan vs Control: P=NS; Results were similar when blood lipids converted to z-scores. | Model adjustments:; Baseline blood lipid, period, carryover effects; Limitations:; - Potential bias due to multiple subgroups and definitions of the outcome; Funding sources:; USDA Agricultural Research Service; National Pecan Shellers Association
Missimer, 2017 (https://pubmed.ncbi.nlm.nih.gov/28146063) ^101^; RCT crossover, U.S.; Baseline N=50, Analytic N=48 (Attrition: 4%); Participant characteristics at baseline: Healthy participants (~50% female) aged ~23 years of age with, on average, normal BMI and blood lipid panel; Summary of findings:; Participants had significantly higher total blood, LDL, and HDL cholesterol after intake of 2 eggs daily for 4 weeks, compared to one packet of oatmeal for breakfast. | Intervention and comparator:; - Eggs (2 per day): 370 mg cholesterol, 10 g fat; - Oatmeal (one packet): 0 mg cholesterol, 1.5-2 g fat; - Participants instructed to eat intervention foods as first meal of the day and were allowed to add additional foods to meal; also instructed to avoid consuming whole eggs or foods containing predominantly eggs or oats.; [underlined: Duration of intervention:] 4 wk each diet (wash-out: 3 wk); [underlined: Compliance:] Monitored by self-report and bi-weekly visit to laboratory for product pickup; 2 participants dropped out due to failed compliance; [underlined: Dietary intake during Egg vs Oatmeal, Mean (SD), g/d:]; SFA: 27.3 (11.9) vs 21.1 (8.1), P<0.001; MUFA: 30.4 (11.6) vs 23.2 (9.6), P<0.001; PUFA: 16.6 (7.4) vs 15.7 (11.5), P=NS; Cholesterol (mg/d): 546.1 (96.6) vs 173.1 (90.6), P<0.001; Other components of diet differed significantly: Total fat (higher in Egg), carbohydrate, soluble fiber, glycemic load (all lower in Egg) | Outcomes and assessment methods:; Fasting blood lipids at baseline and end of each dietary period (4 wk); Levels at follow-up; [underlined: TC], mmol/L, Mean (SD); Egg vs oatmeal: 4.2 (0.7) vs 4.0 (0.7), P<0.025; [underlined: LDL], mmol/L, Mean (SD); Egg vs oatmeal: 2.1 (0.7) vs 1.9 (0.6), P<0.025; [underlined: HDL], mmol/L, Mean (SD); Egg vs oatmeal: 1.71 (0.48) vs 1.62 (0.47), P<0.025; [underlined: Triglycerides], mmol/L, Mean (SD); Egg vs oatmeal: NS | Model adjustments:; None; Limitations:; - No information on randomization of allocation sequence; - Co-interventions (fiber) differed between groups; - No preregistered statistical analysis plan; Funding sources:; Esperance Family Foundation
Morillas-Ruiz, 2014 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4129134/) ^102^; RCT crossover, Spain; Baseline N=60 Analytic N=53 (Attrition: 12%); Participant characteristics at baseline: Healthy post-menopausal, Caucasian women aged ~64y, with 73% overweight or obese, and 38% with hypercholesterolemia; Summary of findings:; Total and LDL cholesterol at the end of a butter, margarine, and olive oil intervention was significantly different between groups. | Intervention and comparator:; - Breakfast A: containing 20 g of butter (SFA); - SFA: 51.4 g; - MUFA: 21 g; - PUFA: 3 g; - Cholesterol: 215 mg; - Breakfast B: containing 20 g of margarine (PUFA); - SFA: 12.8 g; - MUFA: 15.3 g; - PUFA: 29.2 g; - Cholesterol: 0 mg; - Breakfast C: 20 g virgin olive oil (MUFA); - SFA: 14.5 g; - MUFA: 71 g; - PUFA: 10 g; - Cholesterol: 0 mg; [underlined: Duration of intervention:] 4 wk (45 days for each washout period; no run-in period); [underlined: Compliance:] NR | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 wk; [underlined: TC], mg/dL, Mean (SEM) Post-intervention; Butter: 208.21 (4.67); Margarine: 194.15 (3.65); Olive oil: 195.75 (5.19); P=0.050* (which groups differed NR); *described as being significant in the results; [underlined: LDL], mg/dL, Mean (SEM) Post-intervention: NS; Butter: 120.89 (4.01); Margarine: 107.85 (3.10); Olive oil: 111.00 (4.76); P=0.042 (which groups differed NR); [underlined: HDL cholesterol], Post-intervention: NS; [underlined: Triglycerides,] Post-intervention: NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - No preregistered statistical analysis plan prior to start of study; Funding sources:; Catholic University of San Antonio
Morton, 2019 (https://pubmed.ncbi.nlm.nih.gov/30944249/) ^103^; RCT crossover, U.S.; Baseline=NR Analytic N=9 (Attrition: NR); Participant characteristics at baseline: Overweight BMI ~29, low HDL cholesterol (mean 41 mg/dl, range 34-47), ~47 y, 33% female; Summary of findings:; Consumption of a high unsaturated-fat (diet compared to a low-fat, high carbohydrate diet had no significant between group difference in changes to blood lipids in overweight adults with low HDL cholesterol. | Intervention and comparator:; - High unsat-fat (high MUFA): 40% fat (23% MUFA, 7% PUFA, 10% SFA), 45% CHO, 15% protein, 180mg cholesterol; - Low fat (high carbohydrate): 20% fat (8% MUFA, 7% PUFA, 5% SFA), 65% CHO, 15% protein, 90 mg cholesterol; - Controlled feeding trial; Isocaloric diets provided by researchers; [underlined: Duration of intervention:] 4 wk (3 wk washout); [underlined: Compliance:] NR; [underlined: Dietary intake for Low fat vs High fat diet]: NR | Outcomes and assessment methods:; Fasting blood lipids: At baseline and after each feeding period.; Levels at follow-up; [underlined: TC,] mmol/L; High fat vs low fat: NS; [underlined: LDL], mmol/L; High fat vs low fat: NS; [underlined: HDL], mmol/L; High fat vs low fat: NS; [underlined: Triglycerides,] mmol/L; High fat vs low fat: NS | Model adjustments:; None; Limitations:; - No information provided about randomization or period effects; - No data available to asses attrition rate; - No information provided about diet compliance; - Potential bias from missing data; - No preregistered statistical analysis plan for most blood lipid outcomes; Funding sources:; NIH and the National Center for Advancing Translational Science
[underlined: Olmedilla-Alonso, 2017] ^105^; RCT crossover, Spain; Baseline N=30 Analytic N=30 (Attrition: 0%); Participant characteristics at baseline: Healthy adults (53% women) aged ~42 years, BMI of 25.1, no CVD or diabetes, borderline high total and LDL cholesterol; Summary of findings:; No significant differences in the blood lipid concentrations of participants after the intake of semi-skimmed ewe’s milk, whole ewe’s milk or whole cow’s milk yogurt. | Intervention and comparators:; - Semi-skimmed ewe’s milk yogurt (2.8% milk fat); - Whole ewe’s milk yogurt (5.8% milk fat); - Whole Cow’s milk yogurt (3% milk fat); - Participants consumed two yogurts per day (125 g/yogurt); each type in random order; [underlined: Duration of intervention:] 5 wk (4 wk washout period); [underlined: Compliance:] 3-day dietary records from the beginning of each phase used to calculate dietary nutrient intake. No differences found in the dietary macronutrient intake in any of the study periods.; [underlined: Dietary intake for ewe yogurt 2.8% fat and ewe yogurt 5.8% fat, and cow’s milk yogurt, Mean (SD), g/100 g fat day:]; SFA: 77.85 (2.03) vs 79.59 (1.69) vs 73.87 (2.30), P<0.05; MUFA: 19.38 (2.08) vs 17.96 (1.72) vs 23.35 (1.75), P<0.05; PUFA: 2.77 (0.40) vs 2.45 (0.43) vs 2.78 (0.60), P<0.05; Other components of diet differed: protein, fat, n6:n3, n-3, potassium, calcium, and fiber. Ewe’s milk yogurt presented almost double the n-3 ALA than cow’s milk and had a lower n-6:n-3 ratio. | Outcomes and assessment methods:; Fasting blood lipids at the start and end of each period (relative percentage change by intervention period); [underlined: TC], NS; [underlined: LDL], NS; [underlined: HDL], NS; [underlined: Triglycerides], NS; No significant effects were found comparing results stratified by CVD risk (Total/HDL cholesterol index top vs low and moderate tertile, ≥5.1 for men; ≥3.5 for women) | Model adjustments:; None; Limitations:; - No information provided on randomization method; - No preregistered statistical analysis plan; Funding sources:; MINECO (Spanish Ministry of Economy, Industry and Competitiveness); Agro Technological Institute; INIA (National Institute for Agricultural and Food Research and Technology); European Regional Development Fund
Palacios, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/31525129) ^107^; RCT crossover, U.S.; Baseline N=54 Analytic N=33 (Attrition: 39%); Participant characteristics at baseline: Prediabetic adults (49% female) ~48y of age with overweight or obesity. Approximately 50% Caucasian, ~40% Black, and ~12% Hispanic/Latino.; Summary of findings:; Consuming 3 oz of almonds per day for 6 weeks, which increased unsaturated FA intake, did not significantly affect blood lipids compared to energy-matched carbohydrate based foods. | Intervention and comparator:; - Raw almonds, 3.0 oz/d daily; - Sources: Almonds; - Energy-matched CHO-based foods; - Sources: fruit and grain bars, baked potato chips, mini bagels, rice cakes, dinner rolls, pretzels, dried mango slices, pudding cups, vanilla cookie wafers; [underlined: Duration of intervention:] 6 wk (washout ≥4 wk); [underlined: Compliance:] Study product consumption recorded instudy log daily (0%, <50%, or ≥50%); Median (IQL) compliance during Almond: 100% (97.5-100) vs CHO: 98.7% (94.1-100); [underlined: Dietary intake during Almond vs CHO-based foods periods, Mean (SEM):]; SFA (%E): 11.3 (0.5) vs 10.5 (0.5), P=NS; UFA (%E): 35.3 (0.9) vs 21.7 (0.7), P<0.001; MUFA or PUFA: NR; Cholesterol, Median (IQL) (mg/d): 281 (211-423) vs 320 (224-464), P=NS; Other components of diet differed significantly: Total fat, protein, dietary fiber, and magnesium (higher in Almond), CHO and sugar (lower in Almond) | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline and in duplicate at end of 6 wk intervention period.; Comparing percentage change from baseline between groups; [underlined: TC], mg/dL; Almond vs CHO-based foods: P=NS; [underlined: LDL], mg/dL; Almond vs CHO-based foods: P=NS; [underlined: HDL], mg/dL; Almond vs CHO-based foods: P=NS; [underlined: Triglycerides], mg/dL; Almond vs CHO-based foods: P=NS | Model adjustments:; Baseline blood lipid value; Included when p<0.05: sequence and period.; Limitations:; - No information provided on randomization method; - Co-interventions (protein and dietary fiber) not balanced between groups; - Higher percentage of missing data in group who started with CHO-based foods; - Preregistered protocol does not provide sufficient detail on analysis intentions; Funding sources:; Almond Board of California
Palomaki, 2010 (https://pubmed.ncbi.nlm.nih.gov/21122147) ^108^; RCT crossover, Hameenlinna Metabolic Syndrome, Finland; Baseline N=43 Analytic N=37 (Attrition: 14%); Participant characteristics at baseline: Men (30-65 years) with metabolic syndrome, with 21 men being diagnosed with hypertension, 19 with type 2 diabetes and 6 with coronary heart disease; Summary of findings:; Total cholesterol and LDL cholesterol were significantly lower after participants consumed cold-pressed turnip rapeseed oil compared to butter for 6-8 weeks. HDL cholesterol and triglycerides did not differ between groups. | Intervention and comparator:; - Cold-pressed turnip rapeseed oil (CPTRO, 35 mL/day, no heating or frying) (n=20); - Butter (37.5 g/day, no heating or frying) (n=17); [underlined: Duration of intervention:] 6-8 wk (8 wk washout); [underlined: Compliance:] NR; [underlined: Dietary intake for Intervention vs Control:] everyday diet of participants remained stable during the study | Outcomes and assessment methods:; Fasting blood lipids after each period; [underlined: TC], mmol/L, Mean (SEM), Post-intervention; CPTRO: 4.98 (0.23); Butter: 5.43 (0.23); TC is significantly lower after CPTRO (8%) than after butter. P<0.001; [underlined: LDL], mmol/L, Mean (SEM), Post-intervention; CPTRO: 3.00 (0.18); Butter: 3.35 (0.21); LDL cholesterol is significantly lower after CPTRO (11%) than after butter. P<0.001; [underlined: HDL], mmol/L, Mean (SEM); CPTRO vs Butter: NS; [underlined: Triglycerides], mmol/L, Mean (SEM); CPTRO vs Butter: NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - No preregistered statistical analysis plan; Funding sources:; Ministry of Health and Social Welfare in Finland through Medical Research Fund of Kanta-Hame Central Hospital; Hame Regional Fund under Finnish Cultural Foundation; Kankaisten Oljykasvit Ltd; Hilkka and Vaino Kiltti Foundation
Pieters, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/25226826) ^109^; RCT crossover, Netherlands; Baseline N=36 Analytic N=32 (Attrition: 11%); Participant characteristics at baseline: Healthy overweight and obese adults (50% female), with mean BMI ~29, ~51y of age, no active CVD, no medication for hyperlipidemia; Summary of findings:; In healthy overweight and obese adults, an increased intake of echium oil (which provided SDA), compared to high oleic sunflower oil, did not significantly affect blood lipid values. | Intervention and comparator:; - Echium oil (10g/day; provides 1.2 g stearidonic acid (SDA)); - High oleic acid sunflower oil (HOSO) (10g/day); [underlined: Fatty acid composition of Echium oil vs HOSO (% total fat):]; [underlined: SFA]; Palmitic acid: 6.7 vs 3.5; Stearic acid: 3.8 vs 3.2; [underlined: MUFA]; Oleic acid: 15.2 vs 84.2; [underlined: PUFA]; LA: 15.5 vs 7.4; Gamma-LA: 10.8 vs 0; ALA: 32.3 vs 0; Stearidonic acid (C18:4n-3): 12.8 vs 0; Participants instructed to consume 5g oil, provided by researchers, at 2 meals (lunch and dinner) each day; [underlined: Duration of intervention:] 6 wk each diet (2 wk washout period); [underlined: Compliance]: Compliance, as estimated from the returned number of sachets, was 96.2% during the HOSO period and 94.4% during the Echium oil period.; [underlined: Dietary intake for Intervention (EO) vs Control (HOSO), Mean (SD), %E:]; SFA: NS; MUFA: 13.3 (4.5) vs 15.2 (3.8); P=0.02; total PUFA: NS; LA: 10.3 (3.3) vs 8 (3); P<0.01; ALA: 1.7 (0.5) vs 0.4 (0.1); P<0.01; Cholesterol: NS; Protein intake was higher in the intervention arm. No other components of diet differed significantly. | Outcomes and assessment methods:; Fasting blood lipids: Assessed at weeks 0, 3, 5 and 6 of both intervention periods. Values from weeks 5 and 6 were averaged when available.; Levels after end of the two intervention periods; [underlined: TC], mmol/L, Mean (SD), Echium vs HOSO oil: NS; [underlined: LDL], mmol/L, Mean (SD), Echium vs HOSO oil: NS; [underlined: HDL], mmol/L, Mean (SD), Echium vs HOSO oil: NS; [underlined: Triglycerides], mmol/L, Mean (SD), Echium vs HOSO oil: NS | Model adjustments:; None; Limitations:; - No information provided on randomization; - No preregistered statistical analysis plan; Funding sources:; Bioriginal Europe Asia b.v.
Root, 2013 (https://pubmed.ncbi.nlm.nih.gov/25008012/?from_term=DASH-like+diets+high+in+protein+or+monounsaturated+fats+improve+metabolic+syndrome+and+calculated+vascular+risk&from_pos=1) ^111^; RCT crossover, OmniHeart, U.S.; Baseline=191 Analytic N=164 (Attrition: 14%); Participant characteristics at baseline: ~53.6 y, 45% female, BMI ~30.2, 55% African American, 100% high BP or HTN, no HTN or hyperlipidemia medication, no CVD, no diabetes; Summary of findings:; Replacement of 10% carbohydrate by unsaturated fat for 6 weeks significantly reduced blood total cholesterol and triglycerides and increased HDL cholesterol levels in healthy adults with pre- or stage 1 hypertension. | Intervention and comparators:; - Carbohydrate-rich diet (CHO): 58% carbohydrate, 15% protein, 27% fat, 6% SFA, 13% MUFA, 8%PUFA); - Protein-rich diet (PROT): 10% CHO replaced by protein (48% CHO, 25% protein, 27% fat, 6% SFA, 13% MUFA, 8%PUFA); - Unsaturated fat-rich diet (UNSAT): 10% CHO replaced by unsaturated fat (48% CHO, 15% protein, 37% fat, 6% SFA, 21% MUFA, 10%PUFA); - Interventions designed to maintain weight, were low in saturated fat, cholesterol, and sodium.; - Meals prepared in a research kitchen; [underlined: Duration of intervention:] 6 wk (2-4 wk washout); [underlined: Compliance:] 95% of trial person days, i.e. complete consumption of all study foods without any non-study foods; [underlined: Dietary composition of CARBO vs PROT vs UNSAT diet, Mean]:; SFA (%): 6 vs 6 vs 6; MUFA (%): 13 vs 13 vs 21; PUFA (%): 8 vs 8 vs 10; CHO (%): 58 vs 48 vs 48; Cholesterol (mg/1000kcal): 71 vs 71 vs 71; No significant difference in cholesterol, fiber, alcohol and sodium. | Outcomes and assessment methods:; Fasting blood lipids: At baseline and after each feeding period.; [underlined: TC,] mmol/L, change from baseline, Mean (SD); UNSAT: 4.86 (0.91); vs CHO: 4.97 (0.88), P<0.043; vs PROT: 4.73 (0.83), P=0.001; [underlined: HDL], mmol/L, change from baseline, Mean (SD); UNSAT: 1.29 (0.39); vs CHO: 1.26 (0.36), P=0.041; vs PROT: 1.23 (0.34), P<0.001; [underlined: Triglycerides,] mmol/L, change from baseline, Mean (SD); UNSAT: 1.13 (0.65, 1.92); vs CHO: 1.24 (0.73, 2.12), P<0.001; vs PROT: P=NS | Model adjustments:; None; Limitations:; - Attrition >10%; Funding sources:; NIH/NHLBI
Sawrey-Kubicek, 2019 (https://pubmed.ncbi.nlm.nih.gov/31172172) ^115^; RCT crossover, U.S.; Baseline N=23 Analytic N=20 (Attrition: 13%); Participant characteristics at baseline: Overweight/obese postmenopausal women aged 48 to 70 years with HDL >50 mg/dL; Summary of findings:; Consuming whole eggs, which increased dietary cholesterol intake, compared to yolk-free eggs daily for 4 weeks did not significantly change total blood, LDL, HDL cholesterol, and triglycerides. | Intervention and comparator:; - Liquid whole egg (100 g = equivalent to 2 whole eggs); - Yolk-free eggs (100 g = equivalent to 2 egg whites); - Liquid whole egg and yolk-free eggs consumed as part of daily frozen breakfast meals; [underlined: Duration of intervention:] 4 wk each diet (2 wk run-in; 4wk washout); [underlined: Compliance:] 3-day diet records and food containers; Compliance was 98%; [underlined: Dietary intake for Intervention vs Control, Mean (SD), g/day:]; SFA: NS between groups; MUFA: NS between groups; PUFA: NS between groups; Cholesterol: Whole egg: 498.9 (59.7) vs 126.6 (53.8), P<0.001; Other components of diet differed significantly: None | Outcomes and assessment methods:; Fasting blood lipids at baseline and 4 wk follow-up; Change from pre- to post-intervention; [underlined: TC], mg/dL, Mean (SD); Whole egg vs yolk-free eggs: NS; [underlined: LDL], mg/dL, Mean (SD); Whole egg vs yolk-free eggs: NS; [underlined: HDL], mg/dL, Mean (SD); Whole egg vs yolk-free eggs: NS; [underlined: Triglycerides], mg/dL, Mean (SD); Whole egg vs yolk-free eggs: NS | Model adjustments:; None; Limitations:; - No information on potential impact of missing data; - No preregistered statistical analysis plan; Funding sources:; Egg Nutrition Center
Stonehouse, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/31227804) ^118^; RCT crossover, Australia; Baseline N=62 Analytic N=38 (Attrition: 39%); Participant characteristics at baseline: Healthy young adults ~30 y, BMI~23, blood pressure and lipid profile in the normal range.; Summary of findings:; Consumption of palm olein and cocoa butter compared to olive oil for 4 weeks as part of an isocaloric diets resulted in no significant between group differences in changes to total, LDL and HDL cholesterol among young adults. | Intervention and comparators:; - Palm olein (PO) (IV64) (high in saturated fatty acids primarily in the sn-1 and sn-3 positions); - SFA 39%, MUFA 46%, PUFA 13%; - Cocoa butter (CB) (high in saturated fatty acids primarily in the sn-1 and sn-3 positions); - SFA 64%, MUFA 33%, PUFA 3%; - Olive oil, extra virgin (OO) (high in MUFA); - SFA 20%, MUFA 65%, PUFA 15%; - Food provided by researchers. Diets isocaloric: 30-35%E from fat (20% derived from test oils (~44g fat/d)), ~18%E from protein and ~48%E from carbohydrate.; - Study compared oils with unsaturated fatty acids primarily in the sn-2 position. Oils provided in frozen meals and snacks; [underlined: Duration of intervention:] 4 wk each diet (2- wk run-in, 2- wk washout period) during which the PO (IV72) diet was used); [underlined: Compliance]: Monitored via intake checklists and weekly online surveys. Mean compliance for completers were CB 97%, OO 99%, PO IV64 98%; [underlined: Dietary intake for CB vs OO vs PO Diet, mmol/l, Mean (95% CI): NR] | Outcomes and assessment methods:; Fasting blood lipids assessed at baseline at the end of the intervention; Change in lipid values from baseline; [underlined: TC], mmol/l, Marginal means (95%CI); Between group differences: P=0.14,; [underlined: LDL], mmol/l, Marginal means (95%CI); CB: 0.00 (−0.12, 0.12); OO: −0.05 (−0.17, 0.08); PO: 0.07 (−0.01, 0.14); Between group differences: P=0.05; [underlined: HDL], mmol/l, Marginal means (95%CI); Between group differences: P=0.31; [underlined: Triglycerides,] mmol/l, Marginal means (95%CI); Between group differences: P=0.07 | Model adjustments:; Weight change, baseline levels; Limitations:; - Potential missing data bias due to not statistically accounting for missing data; Funding sources: Malaysian Palm Oil Board
Sun, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/29737804) ^119^; RCT crossover, China; Baseline N=120 Analytic N=100 (Attrition: 17%); Participant characteristics at baseline: Healthy adults (53% female) ~40y, BMI~22, no CVD, diabetes, normal blood lipid levels; Summary of findings:; Consumption of a diet with ~20%E from palm olein vs 20%E from olive oil resulted in no significant between group differences in changes to total, LDL-, HDL cholesterol and triglycerides in a healthy Chinese population | Intervention and comparator:; - Palm olein (PO) (48g/d); - Palmitic acid: 28 g/100 g, Oleic acid: 49 g/100 g, LA: 14 g/100 g, ALA: 0.21 g/100 g, AA: 0.23 g/100 g; - Olive oil, extra virgin (EVOO) (48g/d); - Palmitic acid: 10 g/100 g, Oleic acid: 77 g/100 g, LA: 4 g/100 g, ALA: 0.55 g/100 g, AA: 0.34 g/100 g; - Baseline isocaloric diet (only variation oil content) in accordance with Chinese Dietary Reference Intakes; - All meals provided by researchers at the factory canteen; - %E from fat ~30% (80 g); [underlined: Duration of intervention:] 5 wk each test diet (2- wk run-in, 2- wk washout period during which the PO (IV72) diet was used); [underlined: Compliance]: assessed via weighted food record; all participants consumed ~48g of each oil; [underlined: Dietary intake for PO vs OO Diet, mmol/l, Mean]; SFA: NR; MUFA: NR; PUFA: NR; No significant differences in the dietary intake of energy, and macronutrients were observed | Outcomes and assessment methods:; Fasting blood lipids assessed at the beginning and end of the run-in period and at the end of each intervention; Change in lipid values from baseline; between group differences; [underlined: TC], mmol/l, Mean (SD); PO vs EVOO: NS; [underlined: LDL], mmol/l, Mean (SD); PO vs EVOO: NS; [underlined: HDL], mmol/l, Mean (SD); PO vs EVOO: NS; [underlined: Triglycerides,] mmol/l, Mean (SD); PO vs EVOO: NS | Model adjustments:; None; Limitations:; - Potential missing data bias due to not statistically accounting for missing data; - No preregistered statistical analysis plan (plan retrospective); Funding sources:; Malaysian Palm Oil Board, the Fundamental Research Funds for the Center Universities
Teng, 2017 (https://www.ncbi.nlm.nih.gov/pubmed/27642057) ^121^; RCT crossover, Malaysia; Baseline N=54 Analytic N=47 (Attrition: 13%); Participant characteristics at baseline: Abdominally obese participants (~75% female) aged ~33, BMI ~29, without a history of CVD, diabetes or dyslipidemia.; Summary of findings:; Consumption of a high SFA diet for 6 weeks significantly increased total cholesterol and LDL, compared to a diet high in MUFA. Consumption of a high SFA diet for 6 weeks significantly increased HDL cholesterol, compared to replacement of 7%E of SFA with refined carbohydrates. There were no significant differences in triglycerides between groups. | Intervention and comparator diets:; - [underlined: SFA:] 32% total fat (45 g of palm olein and sunflower oil blend); Overall diet: [underlined: 19.7 g SFA], 20.6 g MUFA, 9.7 g PUFA; - [underlined: Carb:] Replacement of 7%E SFA with refined carbohydrate (rose syrup, honey and barley drinks); Overall diet: 1.5 g SFA, 13.5 g MUFA, 5.0 g PUFA from 34 g high oleic sunflower oil blended with sunflower oil; - [underlined: MUFA:] Replacement of SFA with ~7%E MUFA (45 g high oleic sunflower oil blended with sunflower oil); Overall diet: 3.7 g SFA, [underlined: 36.9 g MUFA], 9.1 g PUFA; - All food provided by researchers; - All participants received isocaloric 2000 kcal/d diets; [underlined: Duration of intervention:] 6 wk eat diet; no wash-out reported; [underlined: Compliance:] Attendance and meal intake monitored by nutritionist; compliance (full meal intake) was 97% or higher for all groups; [underlined: Dietary intake during intervention:] NR | Outcomes and assessment methods:; Fasting blood lipids at baseline and 5 and 6 wk after each dietary treatment; Blood lipid levels at 6 wk; [underlined: TC], mmol/L, Mean (95% CI); SFA: 4.89 (4.68, 5.09); Carb: 4.79 (4.58, 4.99); MUFA: 4.71 (4.48, 4.94); SFA vs MUFA: P<0.05; SFA vs Carb: NS; MUFA vs Carb: NR; [underlined: LDL], mmol/L, Mean (95% CI); SFA: 3.05 (2.89, 3.21); Carb: 3.00 (2.84, 3.17); MUFA: 2.89 (2.71, 3.10); SFA vs MUFA: P<0.05; SFA vs Carb: NS; MUFA vs Carb: NR; [underlined: HDL], mmol/L, Mean (95% CI); SFA : 1.23 (1.17, 1.29); Carb: 1.18 (1.13, 1.24); MUFA: 1.21 (1.14, 1.28); SFA vs MUFA: NS; SFA vs Carb: P<0.05; MUFA vs Carb: NR; [underlined: Triglycerides], mmol/L, Mean (95% CI); SFA vs MUFA: NS; SFA vs Carb: NS; MUFA vs Carb: NR | Model adjustments:; None; Limitations:; - No information on whether missing data was different between groups; - No preregistered statistical analysis plan; Funding sources:; Malaysian Palm Oil Board and Malaysian government
Teng, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/20437207) ^122^; RCT crossover, Malaysia; Baseline N=43, Analytic N=41 (Attrition: 5%); Participant characteristics at baseline:; Healthy, normolipidemic subjects, 80% female, mean age 29y, BMI 22, without CVD; Summary of findings:; A diet high in high oleic palm olein (lower in SFA and higher in MUFA and PUFA) consumed over a 5 week period, significantly reduced blood total and LDL cholesterol and triglycerides and increased HDL cholesterol compared to a diet high in unhydrogenated palm stearin in normal weight, normolipidemic adults. | Intervention and comparator:; - High oleic palm olein (HOPO diet: 54% 18:1n-9, 20% 16:0); - Unhydrogenated palm stearin (PST diet: 25% 18:1n-9, 62% 16:0); - All meals provided by researchers; 30-35% fat, 15% protein, 50-55% CHO; - Participants consumed ~54g (accounts for 20-25%E from fat) of test oil incorporated into one cooked meal per day; [underlined: Fatty acid composition of HOPO vs PST (%E):]; SFA: 10.8 vs 16.4; MUFA: 15.3 vs 10.7; Oleic: 15.3 vs 10.7; PUFA: 8.6 vs 3.8; 18:2: 5.8 vs 3.6; 18:3: 2.6 vs 0.2; [underlined: Duration of intervention:] 5 wk each diet (1 wk washout); [underlined: Compliance]: >90% compliance (attendance to the dinner hall); [underlined: Nutrient Composition of HOPO, and PST diets, Mean (SD):]; SFA (%E): 10.8 (0.1), 16.4 (0.1); MUFA (%E): 15.3 (0.1); 10.7 (0.2); PUFA (%E): 8.6 (0.0), 3.8 (0.1); No differences observed in macronutrients. | Outcomes and assessment methods:; Fasting blood lipids measured before and at week 4 and 5 (mean of week 4 and 5 reported); Comparing endpoint values between groups; [underlined: TC], mmol/L, Mean (SD); HOPO diet: 4.48 (0.04); PST: diet: 4.66 (0.04); Between group: P<0.05; [underlined: LDL], mmol/L, Mean (SD); HOPO diet: 2.69 (0.05); PST: diet: 2.95 (0.05); Between group: P<0.05; [underlined: HDL], mmol/L, Mean (SD); HOPO diet: 1.63 (0.03); PST: diet: 1.55 (0.03); Between group: P<0.05; [underlined: Triglycerides], mmol/L, Mean (SD); HOPO diet: 0.83 (0.01); PST: diet: 0.88 (0.01); Between group: P<0.05 | Model adjustments:; Baseline value; Limitations:; - No information provided on randomization method; - Washout period (7 days) may be insufficient to prevent carry-over effects; - No preregistered statistical analysis plan; Funding sources:; Malaysian Palm Oil Board
Tindall, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/31039663) ^124^; RCT crossover, U.S.; Baseline N=45 Analytic N=36 (Attrition: 20%); Participant characteristics at baseline: Adults ~43y of age with overweight or obesity. All with elevated LDL cholesterol and/or elevated BP.; Summary of findings:; In adults with overweight/obesity and elevated LDL cholesterol and/or BP, no significant differences in blood lipids were detected after consumption of a walnut-enriched diet (which increased PUFA/ALA and decreased MUFA) for 6 weeks compared to a walnut-free diet with matched FA profile or an oleic-acid enriched diet that replaced ALA with oleic acid. | Intervention and comparators:; - Diet with walnuts as 18%E (57-99g/d); - Sources: walnuts; - Diet without walnuts but with matched FA profile to walnut diet; - Sources: NA; - Diet without walnuts that replaced 83% ALA with oleic acid; - All diets isocaloric weight maintenance diets; same macronutrient profile; all food provided by the study; [underlined: Duration of intervention:] 6 wk each diet (2 wk run in; washout, Mean=22.8 days, range: 1-164 days); [underlined: Compliance:] Assessed via daily food logs and monitoring participant daily body weight logs; 91% (median); [underlined: Nutrient composition for Walnut vs Walnut-free FA matched vs Oleic acid replace ALA diets, Mean, %E:]; SFA: 7 vs 7 vs 7; MUFA: 9 vs 9 vs 12; PUFA: 16 vs 16 vs 14; ALA: 2.7 vs 2.6 vs 0.4; Cholesterol (mg/d): 117 vs 169 vs 163; Other components of diet differed significantly: Fiber (higher in walnut diet) | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline (end of run-in) and 6 wk; Levels at 6 wk; [underlined: TC], mg/dL; Walnut vs Walnut-free FA matched vs; Oleic acid replace ALA: P=NS; [underlined: LDL], mg/dL; Walnut vs Walnut-free FA matched vs; Oleic acid replace ALA: P=NS; [underlined: HDL], mg/dL; Walnut vs Walnut-free FA matched vs; Oleic acid replace ALA: P=NS; [underlined: Triglycerides], mg/dL; Walnut vs Walnut-free FA matched vs; Oleic acid replace ALA: P=NS | Model adjustments:; Baseline blood lipid; Tested but P=NS: sex, randomization sequence; Limitations:; - Study not blinded; Funding sources:; California Walnut Commission; Pennsylvania State University (PSU) Clinical and Translational Research Institute; PSU Clinical and Translational Science Award; NIH National Center for Advancing Translational Sciences
van Meijl, 2011 (https://www.ncbi.nlm.nih.gov/pubmed/20153619) ^128^; RCT crossover, Netherlands; Baseline N=40 Analytic N=35 (Attrition: 13%); Participant characteristics at baseline: Overweight or obese healthy men (n=10) and women (n=30), ~49.5y, with mean BMI of 32, CVD free, stable weight; Summary of findings:; Intake of low fat dairy products compared to a carbohydrate-rich diet consumed over 8 weeks resulted in a significant decrease in HDL cholesterol and no significant changes in blood total and LDL cholesterol and triglycerides. | Intervention and comparator:; - Low-fat dairy products (n=35); - Sources: 500 mL low-fat milk and 150 g low-fat yogurt; - Carbohydrate-rich control products (n=35); - Sources: 600 mL fruit juice and 3 fruit biscuits; [underlined: Duration of intervention:] 8 wk (2 wk washout period); [underlined: Compliance:] Number of products returned reflected 100% compliance; mean daily intake of 500 mL milk and 150 g yogurt, or 601 mL fruit juice and 43 g fruit biscuits; 1 subject excluded due to non-compliance.; [underlined: Dietary intake for Intervention vs Control, Mean (SD):]; SFA (%E): 12.8 (2.1) vs 10.7 (2.1), P<0.05; MUFA (%E): 10.3 (1.9) vs 9.2 (1.9), P<0.05; PUFA (%E): 6.6 (1.1) vs 6.6 (1.2), P>0.05; Cholesterol (mg/MJ): 23.3 (5.6) vs 19.7 (4.5), P<0.05; TransFA (%E): 0.9 (0.3) vs 0.8 (0.3), P<0.05; Other components of diet differed: carbohydrate, fiber, protein, fat, and calcium. | Outcomes and assessment methods:; Fasting blood lipids at weeks 0, 4, 7, and 8.; Difference in change; [underlined: TC], NS; [underlined: LDL], NS; [underlined: HDL,] mmol/L, Mean; Between group: % Change (95% CI); Dairy vs Control: −2.7,(−0.07, 0.01), P=0.021; (HDL was significantly higher in control than after dairy); [underlined: Triglycerides], NS | Model adjustments:; None; Limitations:; - No information provided on randomization method; - Attrition >10%; - No preregistered statistical analysis plan; Funding sources:; Dutch Dairy Association
Wang, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/25567051) ^131^; RCT crossover, U.S.; Baseline N=45 Analytic N=45 (Attrition: 17%); Participant characteristics at baseline: Predominantly Caucasian and non-Hispanic, aged ~45 years, with overweight or obese, free of CVD or diabetes; Summary of findings:; All 3 diets significantly decreased LDL cholesterol and total cholesterol vs baseline, however, the reduction in LDL cholesterol and total cholesterol by the avocado diet was significantly greater than the low-fat and moderate-fat diets. The low-fat diet (higher in CHO) significantly increased triglycerides compared to the moderate-fat and avocado diets which both significantly decreased triglycerides. | Intervention and comparators:; - LF: Lower-fat diet (n=43) – replacing 6-7%E from SFA with CHO per day (from grains); 24%E total fat, 7% SFA, 11% MUFA, 6% PUFA; - MF: Moderate-fat diet (n=42) – replacing 6-7%E from SFA per day with MUFA using high oleic oils (e.g., sunflower oil and canola oil), 34%E total fat, 6% SFA, [underlined: 17% MUFA], 9% PUFA; - AV: Avocado (n=43) – replacing 6-7%E from SFA with one Hass avocado per day (~13g MUFA), 34%E total fat, 6% SFA, [underlined: 17% MUFA], 9% PUFA; - All food provided by researchers; [underlined: Duration of intervention:] 5 wk each diet (2 wk run-in; 2 wk washout); [underlined: Compliance:] self-reported monitoring; compliance was 90% (# of days participants consumed all study foods and no non-study foods); [underlined: Dietary intake for Intervention vs Control:] diets in the moderate fat and avocado diets were 90% similar. | Outcomes and assessment methods:; Fasting blood lipids at baseline and 5 wk follow-up; [underlined: TC], mg/dL, Mean (SEM); Change from baseline (199.9 (4.8)):; LF: 190.7 (5.1); MF: 188.7 (4.4); AV: 182.2 (4.3); P=0.005; LF vs MF: NS; LF vs AV: P<0.05; MF vs AV: P<0.05; [underlined: LDL], mg/dL, Mean (SEM); Change from baseline (128.1 (3.9)):; LF: 120.5 (4.2); MF: 119.0 (3.7); AV: 113.7 (3.4); P=0.005; LF vs MF: NS; LF vs AV: P<0.05; MF vs AV: P<0.05; [underlined: HDL], mg/dL, Mean (SEM); Change from baseline (48.7 (1.8)):; LF: 44.8 (1.5); MF: 47.2 (1.5); AV: 46.9 (1.6); P=0.02; LF vs MF: P<0.05; LF vs AV: P<0.05; MF vs AV: NS; [underlined: Triglycerides], mg/dL, Mean (SEM); Change from baseline (114.0 (5.9)):; LF: 134.3 (9.8); MF: 111.1 (5.8); AV: 108.6 (7.2); P=0.0005; LF vs MF: P<0.05; LF vs AV: P<0.05; MF vs AV: NS | Model adjustments:; Diet sequence, period and diet period interaction as fixed effect; Limitations:; - None; Funding sources:; Hass Avocado Board; National Center for Research Board
NRCT
Adams, 2010 (https://pubmed.ncbi.nlm.nih.gov/19674491/) ^40^; NRCT crossover, U.S.; Baseline N=10 Analytic N=10 (Attrition: 0%); Participant characteristics at baseline: Mildly hypercholesterolemic men (university faculty and staff) ~49y with BMI ~27; Summary of findings:; Among mildly hypercholesterolemic overweight men, HDL cholesterol was lower and triglycerides was higher after consuming five high SFA, high trans-fatty acid hamburger patties for 5 weeks compared to the same amount of a high MUFA, low trans-fatty acid hamburger patty. No differences were detected for LDL cholesterol. | Intervention and comparator:; - [underlined: 1^st^: High SFA, high trans-fatty acids] hamburger patties (114 g or ~4 oz each x 5/wk): pasture-fed cattle (40 g total fat); - [underlined: 2^nd^: High MUFA, low trans-fatty acids] hamburger (114 g or ~4 oz each x 5/wk): cattle fed grain-based diets (40 g total fat); [underlined: Types of fat in intervention (high SFA) vs control (high MUFA), Mean (SE), g/114 g patty:]; SFA: 16.7 (0.6) vs 14.3 (0.2), P≤0.05; MUFA: 17.1 (0.6) vs 20.2 (0.2), P≤0.01; PUFA: 0.97 (0.03) vs 0.97 (0.06), P=NS; Trans-FA: 1.72 (0.03) vs 1.24 (0.05), P≤0.001; [underlined: Duration of intervention:] 5 wk (3 wk washout); [underlined: Compliance]: Monitored with 3-day diet record and weekly contact with study personnel; Compliance NR; [underlined: Dietary intake for Intervention (high SFA) vs Control (high MUFA) during intervention, Mean (SD), g/d:]; Total fat: 132.3 (13.7) vs 129.2 (14.6), P≤0.01; SFA: 45.0 (4.6) vs 42.7 (4.5), P≤0.05; MUFA: 48.4 (6.6) vs 50.6 (7.2), P≤0.05; Oleic acid: 43.2 (6.4) vs 44.7 (7.0), P≤0.05; PUFA: 13.8 (2.9) vs 13.9 (3.2), P=NS; MUFA:SFA: 1.06 (0.07) vs 1.18 (0.08), P≤0.05; Other components of diet differed significantly: Total energy intake (Higher during High SFA period) | Outcomes and assessment methods:; Fasting blood lipids at baseline and 5 wk follow-up; Comparing levels after 5 wk of intervention vs control; [underlined: LDL], mmol/L, Mean (SE); High SFA vs High MUFA: NS; [underlined: HDL], mmol/L, Mean (SE); High SFA: 0.88 (0.06); High MUFA: 1.06 (0.05); P≤0.05; [underlined: Triglycerides], mmol/L, Mean (SE); High SFA: 3.90 (1.21); High MUFA: 1.72 (0.43); P≤0.05 | Model adjustments:; None; Limitations:; - Not all key confounders adjusted for; - No information on compliance; - No preregistered statistical analysis plan; Funding sources:; YamaBeef Inc., Mabank, TX, U.S.
Sari, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/19647416) ^114^; NRCT (crossover), Turkey; Baseline N=33 Analytic N=32 (Attrition: 3%); Participant characteristics at baseline: Nonsmoking, normolipidemic men ~22y of age in vocational police education school.; Summary of findings:; In young adult men, consumption of pistachios as part of a Mediterranean diet for 4 weeks (which decreased SFA and PUFA intake, but increased MUFA intake) was associated with significantly decreased total blood and LDL cholesterol and triglycerides compared to a Mediterranean diet without pistachios. No association with HDL cholesterol was detected. | Intervention and comparator diets:; - Mediterranean diet with pistachios (~20%E); - Sources: roasted, unsalted pistachios; - Control: Mediterranean diet without pistachios; - Sources: NA; [underlined: Duration of intervention:] 4 wk (no washout period reported); [underlined: Compliance:] Assessed via weighing leftover food; NR; [underlined: Dietary intake for Pistachio vs Control, Mean (SD), %E:]; SFA: 4.8 (1.4) vs 5.9 (1.1), P=0.02; MUFA: 20.2 (2.3) vs 13.3 (1.6), P<0.001; PUFA: 7.1 (1.0) vs 14.2 (1.3), P<0.001; Cholesterol: NR; Other components of diet differed significantly: Fiber (higher in pistachio) | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at baseline and 4 wk; Difference in change; [underlined: TC], mg/dL, Mean (SD); Baseline: 199.6 (41.8); Control: 190.7 (30.1); Pistachios: 149.4 (26.5); P<0.001; [underlined: LDL], mg/dL, Mean (SD); Baseline: 142.0 (37.4); Control: 124.5 (24.5); Pistachios: 95.0 (23.2); P<0.001; [underlined: HDL], mg/dL, Mean (SD); Pistachios vs Control: P=NS; [underlined: Triglycerides], mg/dL, Mean (SD); Baseline: 91.2 (39.7); Control: 112.1 (45.5); Pistachios: 91.1 (38.1); P=0.008 | Model adjustments:; None; Limitations:; - Confounding not addressed; - Co-interventions (dietary fiber) not balanced between groups; - No preregistered statistical analysis plan; Funding sources:; Pistachio Investigation Group of the Gaziantep Chamber of Commerce
Sofi, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/19473822) ^116^; NRCT crossover, Italy; Baseline N=10, Analytic N=10 (Attrition: 0%); Participant characteristics at baseline: Adults ~54y (Median) of age, BMI ~25 with no vascular or inflammatory disease; Summary of findings:; In participants self-selecting their diet, consumption of cheese lower in SFA, and higher in MUFA and PUFA, for 10 weeks did not change fasting blood lipids compared to consumption of cheese higher in SFA and lower in MUFA and PUFA. | Intervention and comparator diets:; - Pecorino cheese, 200g/wk (~7 oz); - Sources: sheep’s cheese; - Control cheese, 200g/wk (~7 oz); - Sources: cow’s cheese; [underlined: Duration of intervention:] 10 wk (washout: 10 wk); [underlined: Compliance:] Monitored via food records and 24 hour recalls; Cheese was consumed “as indicated”; [underlined: FA content for Pecorino cheese vs Control cheese, g/100 lipids:]; ***See paper for detailed description of FAs in cheeses; SFA: ~48 vs ~64; MUFA: ~20 vs ~18.8; PUFA: ~3.5 vs ~2.8; Cholesterol: NR; Other components of diet differed significantly: None | Outcomes and assessment methods:; [underlined: Fasting blood lipids:] Measured at beginning and end of 10wk period; [underlined: TC], mmol/L, Mean (SD); Pecorino vs Control: P=0.8; [underlined: LDL], mmol/L, Mean (SD); Experimental vs Control: P=0.7; [underlined: HDL], mmol/L, Mean (SD); Experimental vs Control: P=0.4; [underlined: Triglycerides], mmol/L, Mean (SD); Experimental vs Control: P=0.7 | Model adjustments:; Age and sex; Limitations:; - Not all key confounders accounted for; - All participants completed study interventions in the same order; - No preregistered statistical analysis plan; Funding sources:; FISR project by the Ministry of Agricultural and Forestry Policies and from the Ministry of University and Research; Ente Cassa de Risparmio di Firenze, Italy.
Sofi, 2013 (https://www.ncbi.nlm.nih.gov/pubmed/23353608) ^117^; NRCT crossover, Italy; Baseline N=NR Analytic N=20 (Attrition: NR); Participant characteristics at baseline: Participants ~53 years (40% female) not taking fish supplements with BMI ~27; Summary of findings:; Among participants who consumed fish fed with 100% fishmeal first, followed by fish fed 50% plant protein and 50% fishmeal, there were no significant differences in total blood, LDL, HDL cholesterol or triglycerides.; Among participants who consumed fish fed with 50% plant protein and 50% fishmeal first, followed by fish fed with 100% fishmeal, total blood cholesterol was significantly higher after consuming fish fed 50% plant protein and 50% fishmeal, compared to after consuming fish fed 100% fishmeals. There were no significant differences in LDL and HDL cholesterol or triglycerides. | Intervention and comparator:; - [underlined: Fishmeal:] Gilthead sea bream fed with 100% fishmeal for 460 days (630 grams or ~22 ounces/wk): n-6/n-3 ratio: 0.42, 2.07 EPA+DHA/100 grams; - [underlined: Plant protein:] Gilthead sea bream fed with 50% fishmeal and 50% plant protein sources for 460 days (soybean meal, corn gluten meal, pea protein isolate) (630 grams or ~22 ounces/wk): n-6/n-3 ratio: 0.84, 1.82 EPA+DHA/100 grams; - Participants instructed to consume 4 servings (630 g) of fish per wk and maintain regular eating pattern; [underlined: Fatty acid composition of filets of fish fed fishmeal vs plant protein, %E:]; SFA: 25.8 vs 23.4, P<0.01; MUFA: 29.9 vs 28.8, P<0.05; n-6 PUFA: 12.3 vs 21.1, P<0.01; n-3 PUFA: 29.5 vs 25.1, P<0.01; n-6:n-3 ratio: 0.42 vs 0.84, P<0.01; [underlined: Duration of intervention:] 10 wk each diet; [underlined: Compliance:] None; [underlined: Dietary intake for Intervention (FM) vs Control (PP), Mean (SD), g/wk:]; SFA: 15.6 (0.8) vs 13.8 (0.6) g, P<0.05; MUFA: 19.3 (1.0) vs 15.9 (0.7), P<0.05; LA: 13.8 (0.6) vs 6.0 (0.2), P<0.01; n6/n3 ratio: 0.48 vs 0.91, P=NR; n-3 PUFA: 16.7 (0.8) vs 15.7 (0.7), P<0.05; n-6 PUFA: 14.1 (0.7) vs 6.6 (0.3), P<0.01; EPA+DHA: 12.5 vs 12.1 (similar between groups); EPA: 4.2 (0.2) vs 4.6 (0.2), P<0.05; Other components of diet differed significantly: None | Outcomes and assessment methods:; Fasting blood lipids at baseline and 10 wk follow-up after each diet; Stratified by crossover order:; Group A (n=10): 1^st^ Fishmeal, 2^nd^ plant protein; [underlined: TC], mg/dL, Mean (95% CI) Fishmeal vs plant protein: NS; [underlined: LDL], mg/dL, Mean (95% CI); Fishmeal vs plant protein: NS; [underlined: HDL], mg/dL, Mean (95% CI); Fishmeal vs plant protein: NS; [underlined: Triglycerides], mg/dL, Mean (95% CI); Fishmeal vs plant protein: NS; Group B (n=10): 1^st^ Plant protein, 2^nd^ fishmeal; [underlined: TC], mg/dL, Mean (95% CI); Fishmeal: 204 (165, 254); Plant protein: 216 (176, 266); P=0.009; [underlined: LDL], mg/dL, Mean (95% CI); Fishmeal vs plant protein: NS; [underlined: HDL], mg/dL, Mean (95% CI); Fishmeal vs plant protein: NS; [underlined: Triglycerides], mg/dL, Mean (95% CI); Fishmeal vs plant protein: NS | Model adjustments:; Age, gender, smoking habit; Limitations:; - Not all key confounders accounted for; - No information on compliance; - No preregistered statistical analysis plan; Funding sources:; Italian Ministry of Education; Universities and Research, the Ministry of Agricultural, Food and Forestry Policies, Ministry of Environment; Ministry of Economic Development
Thompson, 2012 (https://pubmed.ncbi.nlm.nih.gov/22225711/) ^123^; NRCT parallel, CHOICE, U.S.; Baseline N=259 (in trial registry), Analytic N=142 (Attrition: All: ~45%; Control 9.4%, High fat 12.9%, Low fat 11.3%); Participant characteristics at baseline: Women ~55y who completed chemotherapy, radiation, and surgical treatment for breast cancer and were considered cancer free and a BMI between 25 and 34.9; Summary of findings:; Women who completed breast cancer treatment and followed an energy restricted low fat (high carbohydrate) diet had a significantly greater reduction in total and LDL cholesterol and significantly less of a reduction in triglycerides compared to women who followed an energy restricted high fat (low carbohydrate) diet over a 6 month period. No difference in HDL cholesterol was found between groups. | Intervention and comparators:; - Energy restricted High fat/Low carbohydrate diet: 46%E from fat, 32%E from CHO, 22% protein, n=48; - Energy restricted Low fat/High carbohydrate diet: 24%E from fat, 62%E from CHO, 20% protein, n=50; - No diet intervention (n=44), those who were not interested in the weight-loss arms; - Energy restricted diets (deficit of 3500kcal/wk) provided by researchers and distributed 3 times/week; - Both groups lost weight from baseline; [underlined: Diet composition for Low CHO/High fat vs High CHO/Low Fat, Mean (SD):]; Total fat: 64 (3) vs 24 (2); SFA (g): 11 (2) vs 5 (2); MUFA (g): 21 (3) vs 5 (1); PUFA (g): 9 (2) vs 5 (1); Cholesterol (mg): 244 (131) vs 120 (85); Carbohydrate (g): 100 (4) vs 193 (10); Protein (g): 68 (4) vs 62 (6); Fiber (g): 17 (4) vs 26 (5); [underlined: Duration of intervention:] up to 6 months; [underlined: Compliance:] NR; [underlined: Dietary intake for Intervention diets: NR] | Outcomes and assessment methods:; Fasting blood lipids: Assessed at baseline and at approximately one month intervals; Change from baseline to 6 months; [underlined: TC], mg/dL, Mean (SD); High fat vs low fat: P=0.07; Change from baseline:; Control: 0.10 (0.47); vs Low-fat, low weight-loss: −1.56 (0.56), P≤0.05; vs Low-fat, high weight-loss: −3.23 (0.65), P≤0.05; vs High fat, low weight-loss: NS; vs High fat, high weight-loss: −2.65 (0.59), P≤0.05; [underlined: LDL], mg/dL, Mean (SD); High fat vs low fat: P=0.13; Change from baseline:; Control: 0.20 (0.40); vs Low-fat, low weight-loss: NS; vs Low-fat, high weight-loss: −2.30 (0.63), P≤0.05; vs High fat, low weight-loss: NS; vs High fat, high weight-loss: −1.42 (0.57), P≤0.05; [underlined: HDL], mg/dL, Mean (SD); High fat vs low fat: P=0.08; Change from baseline:; Control: 0.20 (0.15); vs Low-fat, low weight-loss: 0.41 (0.17), P≤0.05; vs Low-fat, high weight-loss: NS; vs High fat, low weight-loss: 0.69 (0.19), P≤0.05; vs High fat, high weight-loss: 0.60; [underlined: Triglycerides], mg/dL, Mean (SD); Baseline, Last follow-up:; High fat: 138 (8.9), 97 (6.7); Low fat: 114 (8.7), 100 (6.6); Low fat vs high fat: P=0.01; Change from baseline:; Control: −0.16 (0.62); vs Low-fat, low weight-loss: NS; vs Low-fat, high weight-loss: −2.58 (0.68), P≤0.05; vs High fat, low weight-loss: −2.44 (0.66), P≤0.05; vs High fat, high weight-loss: −4.97 (0.62), P≤0.05 | Model adjustments:; None; Limitations:; - Energy restricted diet; - Study arm assignment was based upon subject preference; - >10% attrition; - Not all key sources of confounding were addressed; - Dietary compliance was not reported; - No preregistered statistical analysis plan; Funding sources:; National Cancer Institute

* Abbreviations: ANOVA – analysis of variance, CHO – carbohydrates, CI – confidence interval, HDL – HDL cholesterol, IQR – interquartile range, kcal – kilocalories, LDL – LDL cholesterol, NR – not reported, NS – non significant, %E – percent energy, PCOS – polycystic ovary syndrome, PRO – protein, SD – standard deviation, SE – standard error, SEM – standard error of the mean, TC – total cholesterol, UFA – unsaturated fatty acids, wk – week(s), y – year(s)

† Statistically significant results bolded.

Table 6 Risk of bias for randomized controlled trials examining types of dietary fat consumed by adults and cardiovascular disease intermediate outcomes (blood lipids)^*,,†^

| Randomization | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result
Abbaspour, 2019,^38^ RCT | Some Concerns | Some Concerns | Low | Low | Some Concerns
Abdullah, 2015,^39^ Crossover RCT | Low | Low | Low | Low | Low
Akrami, 2018,^41^ RCT | Some Concerns | Some Concerns | Some Concerns | Low | Some Concerns
Alphonse, 2017,^42^ Crossover RCT | Some Concerns | Low | Low | Low | Some Concerns
Andraski, 2019,^43^ Crossover RCT | Some Concerns | Some Concerns | Low | Low | Some Concerns
Annuzzi, 2014,^44^ RCT | Low | Low | Low | Low | Some Concerns
Baer, 2019,^45^ Crossover RCT | Low | High | Low | Low | Low
Barbour, 2015,^46^ Crossover RCT | Low | Low | Low | Low | Low
Baxheinrich, 2012,^47^ RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
Beavers, 2010,^48^ RCT | Some Concerns | Low | Low | Low | Some Concerns
Bergeron, 2019,^49^ Crossover RCT | Low | Low | Some Concerns | Low | Some Concerns
Bergeron, 2019,^49^ RCT | Low | Low | High | Low | Some Concerns
Bjermo, 2012,^50^ RCT | Some Concerns | Some Concerns | Low | Low | Some Concerns
Bladbjerg, 2011,^51^ RCT | Some Concerns | Some Concerns | Some Concerns | Low | Some Concerns
Blesso, 2013,^52^ RCT | Some Concerns | Low | Low | Low | Some Concerns
Bos, 2010,^53^ RCT | Low | Some Concerns | Low | Low | Low
Bowen, 2019,^54^ Crossover RCT | Low | Some Concerns | Some Concerns | Low | Some Concerns
Brassard, 2017,^55^ Crossover RCT | Some Concerns | Low | Low | Low | Some Concerns
Burns-Whitmore, 2014,^56^ Crossover RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
Cheng, 2019,^57^ Crossover RCT | Low | Low | Low | Low | Some Concerns
Chinwong, 2017,^58^ Crossover RCT | Some Concerns | Some Concerns | Low | Low | Some Concerns
Chiu, 2014,^59^ RCT | Some Concerns | Low | Low | Low | Some Concerns
Choi, 2018,^60^ Crossover RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
Clayton, 2015,^61^ RCT | Some Concerns | Some Concerns | Some Concerns | Low | Some Concerns
Dawczynski, 2010,^62^ Crossover RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
de Souza, 2018,^63^ RCT | Low | Low | Low | Low | Some Concerns
Dhillon, 2018,^64^ RCT | Low | Low | Low | Low | Some Concerns
Dias, 2017,^65^ RCT | Low | Low | Some Concerns | Low | Some Concerns
Drouin-Chartier, 2015,^66^ Crossover RCT | Some Concerns | Low | Low | Low | Low
Egert, 2010,^67^ RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
Engel, 2015,^68^ Crossover RCT | Some Concerns | Some Concerns | Low | Low | Some Concerns
Faghihnia, 2010,^69^ Crossover RCT | Some Concerns | High | Some Concerns | Low | Some Concerns
Farajbakhsh, 2019,^70^ RCT | Some Concerns | Some Concerns | Low | Low | Some Concerns
Gagliardi, 2010,^71^ RCT | Some Concerns | Some Concerns | Low | Low | Some Concerns
Gilmore, 2011,^72^ Crossover RCT | Some Concerns | Some Concerns | Low | Low | Some Concerns
Grieger, 2014,^73^ RCT | Some Concerns | Low | Low | Low | Some Concerns
Hagen, 2016,^74^ RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
Hallund, 2010,^75^ RCT | Some Concerns | Low | Low | Low | Some Concerns
Harris, 2017,^76^ Crossover RCT | Some Concerns | Low | Low | Low | Some Concerns
Hyde, 2019,^77^ Crossover RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
Iggman, 2014,^78^ RCT | Low | Low | Low | Low | Some Concerns
Intorre, 2011,^79^ Crossover RCT | Some Concerns | Low | Low | Low | Some Concerns
Isherwood, 2010,^80^ Crossover RCT | Low | Low | Low | Low | Some Concerns
Jaakkola, 2017,^81^ RCT | Low | Low | Some Concerns | Low | Some Concerns
Jebb, 2010,^82^ RCT | Low | Low | Some Concerns | Low | Some Concerns
Jones, 2014,^83^ Crossover RCT | Low | Low | Some Concerns | Low | Some Concerns
Kalgaonkar, 2011,^84^ RCT | Some Concerns | Low | High | Low | Some Concerns
Karupaiah, 2016,^85^ Crossover RCT | Some Concerns | Low | Low | Low | Some Concerns
Katz, 2012,^86^ Crossover RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
Kawakami, 2015,^87^ Crossover RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
Khaw, 2018,^88^ RCT | Low | Low | Low | Low | Some Concerns
Klempel, 2013,^89^ RCT | Some Concerns | Low | Low | Low | Some Concerns
Kontogianni, 2013,^90^ Crossover RCT | Some Concerns | Low | High | Low | Some Concerns
Kovell, 2019,^91^ Crossover RCT | Low | Low | Low | Low | Some Concerns
Kruse, 2015,^92^ RCT | Low | Low | Low | Low | Some Concerns
Lim, 2010,^93^ RCT | Some Concerns | Some Concerns | Low | Low | Some Concerns
Liu, 2018,^94^ Crossover RCT | Low | Some Concerns | Low | Low | Low
Lucci, 2016,^95^ RCT | Low | Some Concerns | Low | Low | Some Concerns
Lv, 2018,^96^ RCT | Some Concerns | Low | Low | Low | Some Concerns
McDaniel, 2013,^97^ Crossover RCT | Some Concerns | Low | Low | Low | Some Concerns
McKay, 2018,^98^ Crossover RCT | Low | Low | Low | Low | Some Concerns
Michielsen, 2019,^99^ RCT | Some Concerns | Some Concerns | Low | Low | Some Concerns
Miller, 2016,^100^ RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
Missimer, 2017,^101^ Crossover RCT | Some Concerns | Some Concerns | Low | Low | Some Concerns
Morilla-Ruiz, 2014,^102^ Crossover RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
Morton, 2019,^103^ Crossover RCT | Some Concerns | Some Concerns | Some Concerns | Low | Some Concerns
Ng, 2018,^104^ RCT | Some Concerns | Low | Low | Low | Some Concerns
Olmedilla-Alonso, 2017,^105^ Crossover RCT | Some Concerns | Low | Low | Low | Some Concerns
Ooi, 2012,^106^ RCT | Some Concerns | Low | Low | Low | Some Concerns
Palacios, 2019,^107^ Crossover RCT | Some Concerns | Some Concerns | High | Low | Some Concerns
Palomaki, 2010,^108^ Crossover RCT | Some Concerns | Some Concerns | Some Concerns | Low | Some Concerns
Pieters, 2015,^109^ Crossover RCT | Some Concerns | Low | Low | Low | Some Concerns
Raziani, 2016,^110^ RCT | Low | Low | Low | Low | Low
Root, 2013, Crossover RCT | Low | Low | Some Concerns | Low | Some Concerns
Rozati, 2015,^111^ RCT | Some Concerns | Low | Low | Low | Some Concerns
Rueda, 2013,^113^ RCT | Some Concerns | Some Concerns | Some Concerns | Low | Some Concerns
Sawrey-Kubicek, 2019,^115^ Crossover RCT | Low | Low | Some Concerns | Low | Some Concerns
Sofi, 2013,^117^ Crossover RCT | Some Concerns | High | Some Concerns | Low | Some Concerns
Stonehouse, 2019,^118^ Crossover RCT | Low | Low | Some Concerns | Low | Low
Sun, 2018,^119^ Crossover RCT | Low | Low | Some Concerns | Low | Some Concerns
Tapsell, 2010,^120^ RCT | Low | Some Concerns | Low | Low | Some Concerns
Teng, 2010,^122^ Crossover RCT | Some Concerns | Some Concerns | Low | Low | Some Concerns
Teng, 2017,^121^ Crossover RCT | Low | Low | Some Concerns | Low | Some Concerns
Tindall, 2019,^124^ Crossover RCT | Low | Some Concerns | Low | Low | Low
Utzschneider, 2013,^125^ RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
Vafeiadou, 2015,^126^ RCT | Low | Low | Low | Low | Some Concerns
van der Made, 2014,^127^ RCT | Some Concerns | Low | Low | Low | Some Concerns
van Meijl, 2011,^128^ Crossover RCT | Some Concerns | Low | Low | Low | Some Concerns
Varady, 2011,^129^ RCT | Low | Low | Low | Low | Some Concerns
Veum, 2017,^130^ RCT | Low | High | Low | Low | Some Concerns
Wang, 2015,^131^ Crossover RCT | Low | Low | Low | Low | Low
Werner, 2013,^132^ RCT | Some Concerns | Low | Some Concerns | Low | Some Concerns
Young, 2017,^133^ RCT | Low | Low | Low | Low | Some Concerns
Yubero-Serrano, 2015,^134^ RCT | Low | Low | Low | Low | Some Concerns

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

Table 7 Risk of bias for non-randomized controlled trials examining types of dietary fat consumed by adults and cardiovascular disease intermediate outcomes (blood lipids)^*^

| Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result
Adams, 2010,^40^ Crossover NRCT | Serious | Low | Low | Low | Low | Low | Moderate
Sari, 2010,^114^ NRCT | Serious | Low | Low | Moderate | Low | Low | Moderate
Sofi, 2010,^116^ NRCT | Serious | Low | Low | Low | Low | Low | Moderate
Thompson, 2012,^123^ NRCT | Serious | Low | Low | Moderate | Moderate | Low | Moderate

* Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool (https://www.riskofbias.info/welcome/home/current-version-of-robins-i)” (Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT

Table 8 Evidence from prospective cohort studies examining types of dietary fat consumed by adults and cardiovascular disease endpoint outcomes^*^

Study and Population Characteristics | Exposures, Comparators and Outcomes | Results^†^ | Key Confounders, Study Limitations
Samieri, 2011 (https://pubmed.ncbi.nlm.nih.gov/21676914) ^203^; PCS, 3C (Three-City) Study, France; Baseline N=9,294 Analytic N=7,625 (Attrition: 18%); Participant characteristics at baseline:; - 100% without stroke; - Age: Mean: 73.8y (SD=5.3); - Sex (female): 62%; - Race/ethnicity: NR; - SES: Education: None or primary 25.5%, Secondary 35.9%, High school 20.2%, University 18.4%; - Anthropometry: BMI, Mean: 25.7 (SD=4.0); Fat intake at baseline: NR; Blood lipids and BP at baseline, Mean (SD):; - TC: 5.83 (0.98) mmol/L; - HDL: 1.62 (0.40) mmol/L; - LDL: 3.64 (0.86) mmol/L; - SBP: 146.3 (21.6) mmHg; Summary of findings:; Intensive use of olive oil in both cooking and dressing was significantly associated with lower incidence of stroke compared to no use of olive oil. | Exposures:; - Olive oil (categorical); - No use (n=1,738): 0g (ref); - Moderate use (n=3,052): cooking or dressing; - Intensive use (n=2,835): Both cooking and dressing; [underlined: Assessment method and timing]:; - Self-administered FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 6y (Median 5.25 y) of follow-up; - [underlined: Stroke (nonfatal ischemic or hemorrhagic):] follow-up, medical data including emergency medical service, hospitalization reports, neuroimaging reports, and interview with patient’s physician or family; - [underlined: Stroke]: 148 cases | [underlined: Stroke], HR (95% CI); Olive oil:; No use (ref) vs:; Moderate use: NS; Intensive use: 0.60 (0.38, 0.96), P=0.03*; In unadjusted data, higher olive oil use was associated with lower risk of ischemic stroke (P-trend=0.02) but not hemorrhagic stroke (P-trend NS).; *Similar findings when only controlled for age, sex, education, center, omega-6 rich oils | Key confounders [underlined: NOT] accounted for: Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, SES, TEI, alcohol intake, physical activity, smoking; Additional model adjustments: Center, consumption of fish, meat, pulses, raw vegetables, raw fruits, cooked fruits and vegetables, cereals, regular use of n-3 rich oils, n-6 rich oils, butter, goose or duck fat, SBP, antihypertensive therapy, diabetes, history of CVD, atrial fibrillation, BMI, triglyceridemia, hypercholesterolemia; Limitations:; - Not all key confounders adjusted for; - FFQ was not validated; - Missing data may be unbalanced between exposure groups; - No preregistered statistical analysis plan; Funding sources: Institut National de la Sante et de la Recherche Medicale; Institut de Sante Publique et Developpement of the Victor Segalen Bordeaux 2 University, and sanofi-aventis; Foundation pour la Recherche Medicale; Caisse Nationale Maladie des Travailleurs Salaries, Direction Generale de la Sante, Mutuelle Generale de L’Education Nationale, Institut de la Longeviet; Regional Governments of Aquitaine and Bourgogne; Foundation de France and Ministry of Research – INSERM Programme “Cohortes et Collections de Donnees Biologiques”; ANR
Simila, 2013 (https://pubmed.ncbi.nlm.nih.gov/23534456) ^205^; PCS, ATBC (Alpha-Tocopherol, Beta-Carotene) Cancer Prevention Study, Finland; Baseline N=29,133 Analytic N=21,955 (Attrition: 25%); Participant characteristics at baseline:; - 100% without prevalent CVD; - Age: Mean~57y; - Sex (female): 0%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI: Mean~26; Fat intake at baseline, Mean:; - SFAs: ~17%E; - MUFA: ~11%E; - PUFA: ~11%E; - Trans fat: ~1%E; Blood lipids and BP at baseline, Mean:; - TC: ~6 mmol/L; - HDL: ~1.14 mmol/L; - SBP: Mean~140 mmHg; - DBP: Mean~88 mmHg; Summary of findings:; Replacement of MUFAs with carbohydrates was significantly associated with a higher risk of CHD. Replacement of SFAs or PUFAs with carbohydrates was not associated with risk of CHD. | Exposures:; - Replacement of 2% energy from SFAs, MUFAs and PUFAs (continuous) with 2% energy from:; - Total carbohydrates; - Low-GI carbohydrates; - Medium-GI carbohydrates; - High-GI carbohydrates; [underlined: Assessment method and timing]:; - Self-administered, validated 276-item FFQ to assess diet over previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 19y of follow-up; - [underlined: Incident coronary heart disease (CHD; nonfatal MI or CHD death):] National Hospital Discharge Register, National Register of Causes of Death; - [underlined: CHD:] 4,379 cases; - [underlined: Nonfatal MI:] 2,377 cases; - [underlined: CHD deaths:] 2,002 cases | [underlined: Incident CHD,] relative risk (RR) (95% CI); Replacement of SFAs with:*; Total CHO: NS; Low-GI CHO: NS; Medium-GI CHO: NS; High-GI CHO: NS; Replacement of MUFAs with:*; Total CHO: 1.08 (1.01, 1.16); Low-GI CHO: 1.09 (1.02, 1.16); Medium-GI CHO: NS; High-GI CHO: 1.08 (1.01, 1.15); Replacement of PUFAs with:*; Total CHO: NS; Low-GI CHO: NS; Medium-GI CHO: NS; High-GI CHO: NS; *Analyses without blood lipids and BP resulted in minor changes in risk estimates. | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, SES, family history of CVD or diabetes; Key confounders accounted for: Sex, age, TEI, alcohol intake, physical activity, smoking; Additional model adjustments: Intervention group, BMI, serum total cholesterol and HDL cholesterol, BP, fat subgroups (in each model, the nutrient to be replaced was left out and the model was adjusted for non-substitutive nutrients), protein, Mg, and K; Limitations:; - Not all key confounders adjusted for; - Potential selection bias due to excluding 100% smokers and diabetes; - No preregistered statistical analysis plan; Funding sources:; U.S. Public Health Service contracts from National Cancer Institute; Academy of Finland, Juho Vainio Foundation; Finnish Foundation for Cardiovascular Research
Kouli, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/29124386) ^177^; PCS, ATTICA, Greece; Baseline N=3042 Analytic N=2020 (Attrition: 34%); Participant characteristics at baseline:; - No existing CVD at baseline; - Type 2 diabetes (%): 7; - Age: Mean=45y; - Sex (female): 50%; - Race/ethnicity: 100% Caucasian; - SES: Education, Mean school years: 12; - Anthropometry: BMI, Mean=26; Fat intake at baseline:; - SFA (%E): 10; - MUFA (%E): 23; - MUFA/SFA ratio intake: 1.7; - Trans FA (%E): 0.59; - Olive oil intake: NR; Blood lipids and BP at baseline:; - Hypercholesterolemia (%): 39; - Hypertension (%): 30; Summary of findings:; Exclusive use of olive oil and daily use of olive oil along with other additive fats was associated with statistically significant reduced risk of major cardiovascular disease over approximately 8.4 years among a middle-aged Mediterranean population. | Exposures:; - Olive oil intake at baseline (categorical); - No use: 10.5% (n=212); - Mixed use (daily use of olive oil with other additive fats or exclusive use): 89.5% (n=1808); - Exclusive use in daily cooking 1.1% (n=20); [underlined: Diet assessment method and timing]:; - Validated semi-quantitative FFQ, plus self-reported intake of additional foods and liquids including oils used in cooking (assessed average intake over 12mo); - Administered at baseline; Outcomes and assessment methods:; - Assessed during mean 8.41y of follow-up; - [underlined: Incidence of CVD event] (fatal and non-fatal) ascertained by medical record review; - [underlined: CVD events] (myocardial infarction or stroke): 317 cases (198 men, 119 women) | [underlined: Major cardiovascular event], HR (95% CI); Olive oil intake; No use vs mixed use: 0.91 (0.45, 1.83), P< 0.05*; No use vs exclusive use: 0.07 (0.01, 0.66), P<0.05*; *Association was not altered when adherence to Mediterranean diet and omega-3 fatty acids were included in the model. | Key confounders [underlined: NOT] accounted for:; TEI, family history of CVD or diabetes; Key confounders accounted for: Age, sex, race/ethnicity, SES (education), smoking, alcohol intake, physical activity; Additional model adjustments: BMI, prevalence of diabetes, hypertension and hypercholesterolemia, metabolic syndrome; Limitations:; - Not all key confounders accounted for; - No analyses conducted to address risk of bias from missing data; - No preregistered statistical analysis plan; Funding sources:; Coca-Cola SA; Hellenic Cardiology Society; the Hellenic Atherosclerosis Society
Owen, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/26201872) ^192^; PCS, AusDiab (Australian Diabetes, Obesity and Lifestyle Study), Australia; Baseline N= 11,247, Analytic N~11,217 (Attrition: 0.3%); Participant characteristics at baseline:; - Type 2 diabetes (%): 7.4; - Age: ~53y; - Sex (female): 55%; - Race/ethnicity: NR; - SES: Education: ~17% Bachelor degree/post grad, ~12% associate diploma, ~30% trade/technician, ~40% secondary school; - Anthropometry: BMI, Mean=27; Fat intake at baseline, Median:; - n-3 PUFA (EPA+DPA+DHA) (g/d): Median: Women=0.26; Men=0.33; - DHA (g/d): Median: Women =0.16; Men=0.20; - EPA (g/d) Median: Women =0.07; Men=0.09; - n-6 PUFA (g/d): Mean: Women=8.97; Men=12.03; Blood lipids and BP at baseline: NR; Summary of findings:; Dietary n-3 and n-6 polyunsaturated fat intake was not associated with CVD mortality over 12y follow-up among Australian adults. | Exposures:; - n-3 PUFA (EPA+DHA) intake (quintiles, g/d), (90 cases); - N-6 PUFA intake (quintiles, g/d), (54 cases); [underlined: Diet assessment method and timing]:; - 121 item semi-quantitative FFQ (validated); - Administered at baseline; Outcomes and assessment methods:; - Assessed during median 12.6y of follow-up; - [underlined: CVD mortality] ascertained via linkage to the National Death Index registry; - [underlined: CVD mortality:] 277 cases | [underlined: CVD mortality,] HR (95% CI); n-3 PUFA (quintiles); Q1 (ref) vs Q2, Q3, Q4 or Q5: All NS; P>0.05; n-6 PUFA (quintiles); Q1 (ref) vs Q2, Q3, Q4 or Q5: All NS; P>0.05 | Key confounders [underlined: NOT] accounted for: Race/ethnicity; alcohol intake; Key confounders accounted for: Age, sex, SES (education), TEI, smoking, physical activity, family history of CVD; Additional model adjustments: Diabetes; Limitations:; - Not all key confounders accounted for; - Analysis did not adjust for baseline differences in co-exposures (types of fat); - No preregistered statistical analysis plan; Funding sources: Aus. National Health and Medical Research Council; Aus. Government Dept. of Health and Ageing; Abbott Australasia Pty Ltd; Alphapharm Pty Ltd; Amgen Australia; AstraZeneca; Bristol-Myers Squibb; City Health Centre-Diabetes Service-Canberra; Dept. of Health and Community Services Northern Terr., Department of Health (and Human Services) Tasmania, NSW, WA, SA, Victoria; Diabetes Australia, Diabetes Australia Northern Territory; Eli Lilly Australia, Estate of the Late Edward Wilson; GlaxoSmithKline; Jack Brockhoff Foundation; Janssen-Cilag; Kidney Health Australia, Marian & FH Flack Trust; Menzies Research Institute; Merck Sharp & Dohme; Novartis Pharmaceuticals, Novo Nordisk Pharmaceuticals; Pfizer Pty Ltd; Pratt Foundation; Queensland Health; Roche Diagnostics Australia; Royal Prince Alfred Hospital, Sydney; Sanofi Aventis, sanofi-synthelabo and the Victorian Govt’s OIS Program.
Atkinson, 2011 (https://www.ncbi.nlm.nih.gov/pubmed/21636104) ^139^; PCS, CaPS (Caerphilly Prospective Study), U.K.; Baseline N=2,960, Analytic N=2,710 (Attrition: 9%); Participant characteristics at baseline:; - Age: Mean=53.3y; - Ischemic heart disease (%): 30.3; - Type 2 diabetes (%): 2; - Sex (female): 0%; - Race/ethnicity: NR; - SES: 67% Employed in manual occupations; - Anthropometry: Mean BMI: 26.2; Fat intake at baseline: NR; Blood lipids and BP at baseline, Mean:; - TC (mmol/L): 5.894; - SBP (mmHg): 142.7; - DBP (mmHg): 88.8; Summary of findings:; Dietary intake of saturated and unsaturated fat was not associated with risk of stroke during 18 year follow-up in middle-aged men from the U.K. | Exposures:; - Saturated fat intake, most recent (quintiles, g); - Unsaturated fat intake, most recent (quintiles, g); [underlined: Diet assessment method and timing]:; - Semi-quantitative FFQ, (differed slightly between study phases); - Administered at baseline, 5 and 10y after baseline; - Analysis presented based upon most recent intakes; analysis also conducted on baseline and all diet phases preceding stroke (intake levels not sig different); Outcomes and assessment methods:; - Assessed during median 18y of follow-up; - [underlined: Risk of stroke (fatal and non-fatal)] ascertained via medical and death records and self- or close relative-report; - [underlined: Risk of stroke]: 225 cases (209 ischaemic and 19 haemorrhagic) | [underlined: Risk of stroke,] HR (95% CI); Saturated fat (quintiles); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P=0.67; Unsaturated fat (quintiles); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P=0.13 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, physical activity, family history of CVD or diabetes; Key confounders accounted for: Age, sex, SES, TEI, smoking, alcohol intake; Additional model adjustments: Marital status, vitamin C intake, vegetable fiber intake, BP, cholesterol, BMI, fasting glucose, diabetes, atrial fibrillation; Limitations:; - Not all key confounders accounted for and no adjustment made for time-varying confounding; - Analyses did not account for co-exposures (types of fat); - Potential bias in classification of exposures due to not validated FFQ; - No preregistered statistical analysis plan; Funding sources:; NHS R&D Program on Cardiovascular Disease and Stroke
Lemaitre, 2012 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3396442/) ^180^; PCS, CHS (Cardiovascular Health Study), U.S.; Baseline N=5,888, Analytic N=4,432 (Attrition: 25%); Participant characteristics at baseline:; - No CVD; - Diabetes: Mean~22%; - Age: Median~72y; - Sex (female): 63.9%; - Race/ethnicity: 87% Caucasian; - SES: ~75% > high school; - Anthropometry: BMI, Mean~26; Fat intake at baseline, Mean:; ALA (% total fat): 2.3; Blood lipids and BP at baseline: NR; Summary of findings:; Dietary ALA was not associated with incident congestive heart failure in older adults during 12y follow-up. | Exposures:; - ALA intake (quartiles, % total fat), Median, range; - Q1 0.09, 0.05-0.11; - Q2 0.13, 0.11-0.14; - Q3 0.16, 0.14-0.18; - Q4 0.22, 0.18-0.47; [underlined: Diet assessment method and timing]:; - Picture-sort FFQ (validated) at baseline and 131-item semi quantitative FFQ ~5y later; - Administered at baseline by trained staff; Outcomes and assessment methods:; - Assessed during 12y of follow-up; - Congestive heart failure (CHF) assessed via annual medical exams and phone contact for 10y and phone contact every 6mo thereafter; - [underlined: Total CHF:] 1,072; - [underlined: Nonvalvular CHF:] 696 | ALA; [underlined: Total congestive heart failure,] HR (95% CI),; Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend=0.97; [underlined: Nonvalvular congestive heart failure,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend=0.59 | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes; Key confounders accounted for: Age, sex, SES (education), race/ethnicity, TEI, smoking, alcohol intake, physical activity; Additional model adjustments: Enrollment site, BMI, WC; Limitations:; - Not all key confounders accounted for; - Analyses did not account for co-exposures (types of fat); - No preregistered statistical analysis plan; Funding sources:; NHLBI, National Institute of Neurological Disorders and Stroke; National Institute on Aging
Fretts, 2014 (https://www.ncbi.nlm.nih.gov/pubmed/25159901) ^159^; PCS, CHS, U.S.; Baseline N=5,565 Analytic N=2,583 (Attrition: 54%); Participant characteristics at baseline:; - No CVD; - Diabetes: Mean~9.5%; - Age: Median=73y, IQR: 71.0 - 98.0y; - Sex (female): 63.9%; - Race/ethnicity: 90% Caucasian; - SES: ~37% > high school; - Anthropometry: BMI, Mean~26.5; Fat intake at baseline, Mean:; - SFA (%E): ~10; - ALA: see exposure section; Blood lipids and BP at baseline: NR; Summary of findings:; Dietary ALA was not associated with the risk of total CVD mortality, total CHD mortality, risk of incident CHD or stroke in older adults during 12y follow-up. | Exposures:; - ALA intake (quintiles, % total fat), Median, range; - Q1 1.33, 0.39-1.45; - Q2 1.56, 1.45-1.65; - Q3 1.76, 1.65-1.87; - Q4 2.0, 1.87-2.17; - Q5 2.44, 2.17-4.88; [underlined: Diet assessment method and timing]:; - 131-item semi quantitative FFQ (validated); - Administered at baseline by trained staff; Outcomes and assessment methods:; - Assessed during 12y of follow-up; - Mortality, CHD and stroke assessed via medical records, laboratory/diagnostic reports, death certificates and/or interviews with next of kin.; - [underlined: CVD mortality]: 429 cases; - [underlined: CHD mortality]: 280 cases; - [underlined: Incident CHD]: 378 cases; - [underlined: Incident stroke]: 356 cases; - [underlined: Ischaemic stroke]: 278 cases; - [underlined: Haemorrhagic stroke]: 56 cases | ALA; [underlined: CVD mortality,] HR (95% CI),; Q1 (ref) vs Q2, Q3, Q4 or Q5: All NS; P-trend=0.92; [underlined: CHD mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4 or Q5: All NS; P-trend=0.54; [underlined: Total CHD,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4 or Q5: All NS; P-trend=0.75; [underlined: Incident stroke,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4 or Q5: All NS; P-trend=0.80; [underlined: Ischaemic stroke,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4 or Q5: All NS; P-trend=0.29; [underlined: Haemorrhagic stroke,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4 or Q5: All NS; P-trend=0.16 | Key confounders [underlined: NOT] accounted for:; Physical activity, family history of CVD or diabetes; Key confounders accounted for: Age, sex, SES (education), race/ethnicity, TEI, smoking, alcohol intake; Additional model adjustments: Enrollment site, BMI, diabetes, treated hypertension; Limitations:; - Not all key confounders accounted for; - It is unclear whether those excluded for incomplete dietary data differed from responders; - Analyses did not account for SFA as a co-exposure; - No preregistered statistical analysis plan; Funding sources:; NHLBI, NIA
Okada, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/29899172) ^190^; PCS, CIRCS (Circulatory Risk in Communities Study), Japan; Baseline N=3289, Analytic N=2292 (Attrition: 30%); Participant characteristics at baseline:; - Adults 40-59y of age without history of MI, or stroke at baseline; - Type 2 diabetes: Men~6%; Women ~2%; - Age: Mean~49y; - Sex (female): 48%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI, Mean~23.4; Fat intake at baseline from the breakfast meal, Mean:; - SFA (g/d): 2.6 g (men and women); - MUFA (g/d): 1.6 g (men and women); - PUFA (g/d): 2.6 g; Blood lipids and BP at baseline:; - NR; Summary of findings:; SFA and MUFA intake at breakfast by men, but not women, was significantly associated with reduced incidence of intracerebral hemorrhage during 25 years of follow-up. PUFA intake at breakfast was not significantly associated with incidence of intracerebral hemorrhage in men or women during 25 years of follow-up. | Exposures:; - SFA, MUFA, PUFA intake at breakfast in men (women’s intake NR); - SFA (quartiles; g), Median (range):; - Q1: 0.5 (0.0–0.8); - Q2: 1.2 (0.8–1.9); - Q3: 2.5 (1.9–4.0); - Q4: 6.0 (4.0–22.1); - MUFA (quintiles; g), Median (range):; - Q1: 0.4 (0.0–0.9); - Q2: 1.7 (0.9–2.4); - Q3: 3.2 (2.4–4.5); - Q4: 6.4 (4.5–19.6); - PUFA (quintiles; g), Median (range):; - Q1: 0.7 (0.0–1.3); - Q2: 1.7 (1.3–2.2); - Q3: 2.8 (2.2–3.6); - Q4: 5.0 (3.6–18.5); [underlined: Assessment method and timing]:; - 24-hour recall; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during median 24.6y of follow-up; - [underlined: Intracerebral hemorrhage:] Obtained through death certificates, from public health nurses, local physicians, volunteers, insurance claims, and an annual cardiovascular risk survey.; - [underlined: Intracerebral hemorrhage]: 230 cases | [underlined: Intracerebral hemorrhage,] HR (95% CI); SFA; Men; Q1 (ref) vs Q2: 1.19 (0.58–2.43); Q1 (ref) vs Q3: 0.44 (0.17–1.18); Q1 (ref) vs Q4: 0.22 (0.06–0.79); P=0.008; Women:; Data NR, NS; MUFA; Men; Q1 (ref) vs Q2, Q3: All NS; Q1 vs Q4: 0.21 (0.05-0.86); P-trend: 0.06; Women: data NR, NS; PUFA; Men; Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend: 0.43 (men),; Women: data NR: NS | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, SES, physical activity family history of CVD or diabetes; Key confounders accounted for: Sex, age, TEI, smoking, alcohol intake; Additional model adjustments: Community, nutrient intakes from other meals, and also protein, saturated fat and carbohydrate intakes from breakfast, BMI, serum triglycerides, TC, SBP, use on antihypertensive medication and diabetes; Limitations:; - Not all key confounders accounted for; - Dietary data not validated and only pertained to intake during breakfast; - No preregistered statistical analysis plan; Funding sources:; Japan Society for the Promotion of Science
Jakobsen, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/20375186) ^170^; PCS, DDCH (Danish Diet, Cancer and Health), Denmark; Baseline N=57,053 Analytic N=53,644 (Attrition: 4%); Participant characteristics at baseline:; - Native Danish citizens aged 50-64y without prior diagnosis of cancer, MI, or diabetes mellitus; - Age: Median=56y, 80% central range (51-63); - Sex (female): ~53%; - Race/ethnicity: NR; - SES: >10y of education, 21%; - Anthropometry: BMI, Median=25, 80% central range (21-31); Fat intake at baseline, Median (80% central range):; - SFA (%E): 14 (11-18); - MUFA (%E): 12 (10-15); - PUFA (%E): 6 (4-8); Blood lipids and BP at baseline:; - Hypertension: 15%; Summary of findings:; Replacing SFA intake with high-glycemic index CHO intake at ~56y of age was significantly associated with higher risk of incident MI during ~12.0y of follow-up in men alone, and men and women combined; the association was not significant in women. Replacing SFA intake with low- or medium-glycemic index CHO or total CHO was not significantly associated with incident MI. | Exposures:; - Replacement of SFA with CHO (continuous; per 5% increase in CHO, 5% decrease in SFA); - Replacement of SFA with CHO of differing glycemic index (GI) values (per 5% increase in CHO, 5% decrease in SFA); - Low-GI CHO (first tertile); - Medium GI CHO (second tertile); - High GI CHO (third tertile); [underlined: Assessment method and timing]:; - Validated, semi-quantitative, 192-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~12.0y of follow-up; - [underlined: Incident MI (fatal and nonfatal):] Obtained via linkage with central Danish registries; - Men: 1406 cases; - Women: 537 cases | Replacement of SFA with CHO; [underlined: Incident MI,] HR (95% CI); All: 1.04 (0.92, 1.17); Men: 1.05 (0.92, 1.21); Women: 1.02 (0.82, 1.28); Replacement of SFA with Low-GI CHO; [underlined: Incident MI,] HR (95% CI); All: 0.88 (0.72, 1.07); Men: 0.83 (0.65, 1.04); Women: 1.17 (0.80, 1.71); Replacement of SFA with Medium-GI CHO; [underlined: Incident MI,] HR (95% CI); All: 0.98 (0.80, 1.21); Men: 1.08 (0.84, 1.38); Women: 0.80 (0.54, 1.18); Replacement of SFA with High-GI CHO; [underlined: Incident MI,] HR (95% CI); All: 1.33 (1.08, 1.64); Men: 1.34 (1.04, 1.71); Women: 1.10 (0.75, 1.63) | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (education level), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: BMI; history of hypertension, intake of glycemic CHO, proteins, MUFA, and PUFA (all %E).; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; European Commission 6^th^ Framework Programme; Danish Council for Strategic Research
Joensen, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/19825219) ^171^; PCS, DDCH (Danish Diet, Cancer and Health), Denmark; Baseline N=57,053 Analytic N=53,803 (Attrition: 6%); Participant characteristics at baseline:; - Native Danish citizens aged 50-64y without prior diagnosis of cancer or acute coronary syndrome (ACS); - Age: Median~56y; - Sex (female): ~54%; - Race/ethnicity: NR; - SES: <8y of education, 33%; - Anthropometry: BMI >25, 64.7% of men and 48.2% of women; Fat intake at baseline, Median (IQR):; - n-3 PUFA (g/d), men: 0.70 (0.47, 1.00), women: 0.57 (0.38, 0.83); - EPA (g/d), men: 0.18 (0.11, 0.27), women: 0.15 (0.09, 0.23); - DHA (g/d), men: 0.43 (0.29, 0.63), women: 0.36 (0.24, 0.52); - DPA (g/d), men: 0.08 (0.06, 0.10), women: 0.06 (0.04, 0.08); Baseline blood lipids & BP, Median (IQR):; - TC (mmol/L), men: 5.9 (5.2, 6.7), women: 6.2 (5.4, 7.0); - SBP (mmHg), men: 140 (128, 154), women: 136 (122, 151); Summary of findings:; In men, marine n-3 PUFA intake at ~56y of age was not significantly associated with risk of acute coronary syndrome during ~7.6y of follow-up, although risk tended to be lower with higher intakes. Except one comparison that showed higher risk when comparing Q4 of EPA intake to Q1, marine n-3 PUFA intake in women at ~56y of age was not associated with ACS. | Exposures:; - Marine n-3 PUFA (quintiles; g/d); - Q1 (ref; Men: 0-0.39, Women: 0-0.38); - Q2 (Men: 0.39-0.58, Women: 0.38-0.57); - Q3 (Men: 0.58-0.79, Women: 0.57-0.76); - Q4 (Men: 0.79-1.08, Women: 0.76-1.02); - Q5 (Men >1.08, Women >1.02); - EPA (quintiles; g/d); - Q1 (ref; Men: 0-0.09, Women: 0-0.08); - Q2 (Men: 0.09-0.14, Women: 0.08-0.13); - Q3 (Men: 0.14-0.20, Women: 0.13-0.19); - Q4 (Men: 0.20-0.28, Women: 0.19-0.24); - Q5 (Men >0.28, Women >0.24); - DPA (quintiles; g/d); - Q1 (ref; Men: 0-0.05, Women: 0-0.04); - Q2 (Men: 0.05-0.07, Women: 0.04-0.06); - Q3 (Men: 0.07-0.09, Women: 0.06-0.07); - Q4 (Men: 0.09-0.11, Women: 0.07-0.09); - Q5 (Men >0.11, Women >0.09); - DHA (quintiles; g/d); - Q1 (ref; Men: 0-0.23, Women: 0-0.20); - Q2 (Men: 0.23-0.35, Women: 0.20-0.32); - Q3 (Men: 0.35-0.48, Women: 0.32-0.43); - Q4 (Men: 0.48-0.65; Women: 0.43-0.59); - Q5 (Men: >0.65, Women >0.59); [underlined: Assessment method and timing]:; - Validated, semi-quantitative, 192-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~7.6y of follow-up; - [underlined: Incident acute coronary syndrome (ACS):] Obtained via linkage with central Danish registries; Included unstable angina pectoris, non-fatal MI, and fatal MI; - Men: 852 cases; - Women: 272 cases | Marine n-3 (EPA+DPA+DHA) PUFA; [underlined: ACS,] HR (95% CI); Men:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; Women:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; EPA; [underlined: ACS,] HR (95% CI); Men:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; Women:; Q1 (ref) vs Q2: 0.92 (0.62, 1.36); Q1 (ref) vs Q3: 1.11 (0.75, 1.66); Q1 (ref) vs Q4: 1.57 (1.04, 2.38); Q1 (ref) vs Q5: 0.93 (0.60, 1.42); DPA; [underlined: ACS,] HR (95% CI); Men:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; Women:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; DHA; [underlined: ACS,] HR (95% CI); Men:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; Women:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, SES, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (education level), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: BMI, history of diabetes mellitus, SBP, total cholesterol, intake of fruit, vegetables, SFA, MUFA, and n-6 PUFA; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; NR
Bork, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/27169831) ^148^; PCS, DDCH (Danish Diet, Cancer and Health), Denmark; Baseline N=57,053 Analytic N=53,901 (Attrition: 7%); Participant characteristics at baseline:; - Native Danish citizens aged 50-64y without prior diagnosis of cancer or MI; - Age: Median~56y; - Sex (female): 52%; - Race/ethnicity: NR; - SES: Education, ~33% ≤7y, ~46% 8-10y, ~21% >10y; - Anthropometry: BMI ≥25, 64.7% of men, 48.0% of women; Fat intake at baseline, Median (2.5^th^, 97.5^th^ percentiles):; - ALA (g/d), Men: 2.1 (1.1, 3.6); - ALA (g/d), Women: 1.5 (0.9, 2.7); - LA (g/d), Men: 12.5 (7.0, 21.6); - LA (g/d), Women: 9.6 (5.3, 17.4); - Marine n-3 FA (g/d), Men: 0.7 (0.2, 1.8); - Marine omega-3 FA (g/d), Women: 0.6 (0.1, 1.5); Blood lipids and BP at baseline:; - Hypercholesterolemia: ~6.8%; - Hypertension: ~15.9%; Summary of findings:; In men and women, ALA intake at ~56y of age was not associated with incident MI during ~17y of follow-up. | Exposures:; - ALA (continuous; energy adjusted g/d); - ALA (quintiles; energy adjusted g/d); - Q1 (ref; Men <1.67, Women <1.24); - Q2 (Men 1.67-1.94, Women 1.24-1.43); - Q3 (Men1.94-2.19, Women 1.43-1.62); - Q4 (Men 2.19-2.54, Women 1.62-1.88); - Q5 (Men ≥2.54, Women ≥1.88); - ALA x LA interaction (quintiles; energy adjusted g/d); - ALA x marine omega-3 FA interaction (quintiles; energy adjusted g/d); [underlined: Assessment method and timing]:; - Validated, semi-quantitative, 192-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~17y of follow-up; - [underlined: Incident MI (fatal and nonfatal):] Obtained via linkage with Danish nationwide registers; - [underlined: Total:] 2124 cases in men, 854 cases in women; - [underlined: Fatal:] 417 cases in men | [underlined: Incident MI (total),] HR (95% CI); Men:; ALA (continuous); Data NR, P=0.838; ALA (quintiles); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.299; ALA x LA interaction (quintiles); P-interaction=0.355; ALA x marine omega-3 FA interaction (quintiles); P-interaction=0.576; Women:; ALA (continuous); Data NR, P=0.308; ALA (quintiles); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.746; ALA x LA interaction (quintiles); P-interaction=0.703; ALA x marine omega-3 FA interaction (quintiles); P-interaction=0.572; [underlined: Incident MI (fatal),] (95% CI); Men:; ALA (continuous); Data NR, P=0.328; ALA (quintiles); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.401 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (length of education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: BMI, WC, fiber intake, glycaemic load, MUFA intake, PUFA intake, LA intake, SFA intake, marine-long chain omega-3 FA intake; In women: menopausal status, hormone replacement therapy.; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; NR
Gammelmark, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/27189437) ^160^; PCS, DDCH (Danish Diet, Cancer and Health), Denmark; Baseline N=57,053 Analytic N=54,904 (Attrition: 4%); Participant characteristics at baseline:; - Native Danish citizens aged 50-64y without prior diagnosis of cancer, MI, or cardiac arrest; - Age: Median~56y; - Sex (female): ~53%; - Race/ethnicity: NR; - SES: Education, ~33% Basic school, ~46% Higher education (1-3y), ~21% Higher education (>3y); - Anthropometry: BMI, Median~25; Fat intake at baseline, Median (5^th^-95^th^ percentiles):; - Marine n-3 PUFA (mg/d); - Men: 692.2 (313.7-1370.1); - Women: 569.2 (248.8-1148.3); - EPA (mg/d); - Men: 177.3 (68.7-379.1); - Women: 147.5 (56.1-321.7); - DPA (mg/d); - Men: 82.0 (47.3-134.5); - Women: 61.8 (33.7-105.1); - DHA (mg/d); - Men: 430.7 (189.2-866.1); - Women: 358.3 (151.7-726.9); Blood lipids and BP at baseline:; - Hypercholesterolemia: ~7%; - Hypertension: ~16%; Summary of findings:; In men and women, total marine n-3 PUFA intake, or EPA, DPA, and DHA intake, at ~56y of age, was not significantly associated with incident MI during ~17.0y of follow-up. | Exposures:; - Total marine n-3 PUFA (quintiles; mg/d); - Q1 (ref; Men 0-421, Women 0-341); - Q2 (Men >421-602, Women >341-491); - Q3 (Men >602-793, Women >491-656); - Q4 (Men >793-1083, Women >656-904); - Q5 (Men >1083, Women >904); - EPA (quintiles; mg/d); - Q1 (ref; Men 0-99, Women 0-82); - Q2 (Men >99-151, Women >82-125); - Q3 (Men >151-207, Women >125-173); - Q4 (Men >207-294, Women >173-247); - Q5 (Men >294, Women >247); - DPA (quintiles; mg/d); - Q1 (ref; Men 0-58, Women 0-42); - Q2 (Men >58-74, Women >42-56); - Q3 (Men >74-91, Women >56-69); - Q4 (Men >91-113, Women >69-88); - Q5 (Men >113, Women >88); - DHA (quintiles; mg/d); - Q1 (ref; Men >257, Women 0-211); - Q2 (Men >257-373, Women >211-307); - Q3 (Men >373-496, Women >307-413); - Q4 (Men >496-683, Women >413-573); - Q5 (Men >683, Women >573); [underlined: Assessment method and timing]:; - Validated, semi-quantitative, 192-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~17.0y of follow-up; - [underlined: Incident MI (fatal and nonfatal):] Obtained via linkage with Danish National Patient Registry and/or Danish Causes of Death Registry; - Total: 2136 cases in men, 892 cases in women; - Fatal: 424 cases in men, 156 cases in women | Total marine n-3 (EPA+DPA+DHA) PUFA; [underlined: Incident MI (total),] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.49; Women: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.56; [underlined: Incident MI (fatal),] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.58; Women: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.22; EPA; [underlined: Incident MI (total),] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.69; Women: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.73; DPA; [underlined: Incident MI (total),] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.74; Women: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.46; DHA; [underlined: Incident MI (total),] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.44; Women: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.49; Analyses adjusted for diabetes mellitus, hypertension, and hypercholesterolemia instead of dietary covariates obtained similar results. See Gammelmark, 2016 for details. | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (education level), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: WC (adjusted for BMI), total intake of SFA, MUFA and PUFA (excluding n-3 PUFA), dietary fiber.; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; The Danish Heart Foundation; the Hertha Christensen Foundation; the Danish Cancer Society
Veno, 2017 (https://www.ncbi.nlm.nih.gov/pubmed/29070717) ^212^; PCS, DDCH (Danish Diet, Cancer and Health), Denmark; Baseline N=57,053 Analytic N=55,338 (Attrition: 3%); Participant characteristics at baseline:; - Native Danish citizens aged 50-64y without prior diagnosis of cancer or stroke; - Age: Median=56.1y, 5^th^-95^th^ percentiles (50.7-64.2y); - Sex (female): 52.4%; - Race/ethnicity: NR; - SES: Education, 32.8% ≤7y, 46.1% 8-10y, 21.1% >10y; - Anthropometry: BMI, Median=25.5, 5^th^-95^th^ percentiles (20.5-33.3); Fat intake at baseline, Median (5^th^-95^th^ percentiles):; - LA (g/d): 10.7 (5.2-20.6); - SFA (g/d): 31.1 (15.8-55.3); - MUFA (g/d): 27.2 (14.4-48.6); - Marine n-3 PUFA (g/d): 0.6 (0.2-1.5); Blood lipids and BP at baseline:; - Hypercholesterolemia: 7.3% (Unknown=42.4%); - Hypertension: 16.0% (Unknown=13.1%); Summary of findings:; In men and women, LA intake at ~56y of age, modeled to replace SFA, MUFA, or Glycemic CHO intake, was not significantly associated with total ischemic stroke or any ischemic stroke subtypes during ~13.5y of follow-up except for risk of small vessel occlusion with was lower when LA intake replaced MUFA intake. | Exposures:; - LA (continuous; per 5%E increase) replacing:; - SFA (per 5%E decrease); - MUFA (per 5%E decrease); - Glycemic CHO (per 5%E decrease); [underlined: Assessment method and timing]:; - Validated, semi-quantitative, 192-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~13.5y of follow-up; - [underlined: Ischemic stroke and subtypes:] Obtained via linkage with Danish National Patient Register, validated by physician; - [underlined: Total:] 1879 cases; - [underlined: Large artery atherosclerosis:] 319 cases; - [underlined: Small vessel occlusion:] 844 cases; - [underlined: Cardioembolism:] 102 cases; - [underlined: Strokes of other etiology:] 98 cases; - [underlined: Undetermined etiology:] 516 cases | LA replacing SFA; [underlined: Total ischemic stroke,] HR (95% CI); 0.98 (0.83, 1.16); [underlined: Ischemic stroke subtypes,] HR (95% CI); Large artery atherosclerosis: P=NS; Cardioembolism: P=NS; Small vessel occlusion: P=NS; Stroke of other etiology: P=NS; Stroke of undetermined etiology: P=NS; Noncardioembolic stroke: P=NS; LA replacing MUFA; [underlined: Total ischemic stroke,] HR (95% CI); 0.80 (0.63, 1.02); [underlined: Ischemic stroke subtypes,] HR (95% CI); Large artery atherosclerosis: P=NS; Cardioembolism: P=NS; Small vessel occlusion: 0.67 (0.46, 0.96); Stroke of other etiology: P=NS; Stroke of undetermined etiology: P=NS; Noncardioembolic stroke: P=NS; LA replacing Glycemic CHO; [underlined: Total ischemic stroke,] HR (95% CI); 0.92 (0.78, 1.09); [underlined: Ischemic stroke subtypes,] HR (95% CI); Large artery atherosclerosis: P=NS; Cardioembolism: P=NS; Small vessel occlusion: P=NS; Stroke of other etiology: P=NS; Stroke of undetermined etiology: P=NS; Noncardioembolic stroke: P=NS; Analyses that [underlined: did not adjust] for lifestyle factors, but [underlined: did adjust] for hypertension, hypercholesterolemia, diabetes mellitus, atrial fibrillation/atrial flutter, were similar in direction but achieved statistical significance for total ischemic stroke (LA replacing SFA), small vessel occlusion (LA replacing MUFA or Glycemic CHO), and noncardioembolic stroke (LA replacing SFA, MUFA, or Glycemic CHO). See Veno, 2017 for details. | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (length of education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: WC (adjusted for BMI).; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; The Danish Heart Foundation; The Danish Cancer Society
Bork, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/29767732) ^149^; PCS, Danish Diet, Cancer and Health, Denmark; Baseline N=57,053 Analytic N=55,018 (Attrition: 4%); Participant characteristics at baseline:; - Native Danish citizens aged 50-64y without prior diagnosis of cancer or stroke; - Age: Median~56y; - Sex (female): 52%; - Race/ethnicity: NR; - SES: Education, ~33% ≤7y, ~46% 8-10y, ~21% >10y; - Anthropometry: WC adjusted for BMI, ~88.9 cm; Fat intake at baseline, Median (2.5^th^, 97.5^th^ percentiles):; - ALA (g/d): 1.8 (0.9, 3.3); Blood lipids and BP at baseline:; - Hypercholesterolemia: 7.3%; - Hypertension: 16.0%; Summary of findings:; In men and women, ALA intake at ~56y of age was not associated with ischemic stroke during ~13.5y of follow-up. | Exposures:; - ALA (continuous; energy adjusted g/d); - ALA (quintiles; energy adjusted g/d); - Q1 (ref; ≤1.35); - Q2 (1.36-1.62); - Q3 (1.63-1.90); - Q4 (1.91-2.26); - Q5 (≥2.27); [underlined: Assessment method and timing]:; - Validated, semi-quantitative, 192-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~13.5y of follow-up; - [underlined: Ischemic stroke and subtypes:] Obtained via linkage with Danish National Patient Register, validated by physician; - [underlined: Total:] 1859 cases; - [underlined: Large artery atherosclerosis:] 316; - [underlined: Small vessel occlusion:] 835; - [underlined: Cardioembolism:] 102; - [underlined: Stroke of other etiology:] 98 cases; - [underlined: Stroke of undetermined etiology:] 508 cases | [underlined: Total ischemic stroke,] HR (95% CI); ALA (continuous); Data NR, P=0.431; ALA (quintiles); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.333; Similar NS results seen in analyses that assessed risk of different ischemic stroke subtypes (large artery atherosclerosis, small-vessel occlusion, cardio-embolism, stroke of other etiology, stroke of undetermined etiology). See Bork, 2018 for more details. | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (length of education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: WC (adjusted for BMI), fiber intake, glycaemic load, MUFA intake, PUFA intake, SFA intake, LA intake, marine omega-3 FA intake.; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; The Danish Heart Foundation; The Danish Cancer Society
Veno, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/30602356) ^211^; PCS, Danish Diet, Cancer and Health, Denmark; Baseline N=57,053 Analytic N=55,338 (Attrition: 3%); Participant characteristics at baseline:; - Native Danish citizens aged 50-64y without prior diagnosis of cancer or stroke; - Age: Median=56.1y, 5^th^-95^th^ percentiles (50.7-64.2y); - Sex (female): 52.4%; - Race/ethnicity: NR; - SES: Education, 32.9% ≤7y, 46.1% 8-10y, 21.1% >10y; - Anthropometry: Median=25.5, 5^th^-95^th^ percentiles (20.5-33.3); Fat intake at baseline: NR; Blood lipids and BP at baseline:; - Hypercholesterolemia: 7.4% (Unknown=42.4%); - Hypertension: 16.0% (Unknown=13.4%); Summary of findings:; In men and women, marine n-3 PUFA intake at ~56y of age was not associated with total ischemic stroke during ~13.5y of follow-up, except for higher intakes of DPA, which were associated with higher risk of total ischemic stroke. Higher intakes of total marine n-3 PUFA, EPA, and DHA were associated with lower risk of ischemic stroke due to large artery atherosclerosis and higher risk of ischemic stroke due to cardioembolism. Higher intakes of DPA were associated with higher risk of ischemic stroke due to cardioembolism. | Exposures:; - Total marine n-3 PUFA (quartiles; energy adjusted g/d); - EPA (quartiles; energy adjusted g/d); - DPA (quartiles; energy adjusted g/d); - DHA (quartiles; energy adjusted g/d); [underlined: Assessment method and timing]:; - Validated, semi-quantitative, 192-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~13.5y of follow-up; - [underlined: Ischemic stroke and subtypes:] Obtained via linkage with Danish National Patient Register, validated by physician; - [underlined: Total:] 1879 cases; - [underlined: Large artery atherosclerosis:] 319 cases; - [underlined: Cardioembolism:] 102 cases; - [underlined: Small vessel occlusion:] 844 cases; - [underlined: Stroke of other cause:] 98 cases; - [underlined: Stroke of undetermined cause:] 516 cases | Total marine n-3 PUFA; [underlined: Total ischemic stroke,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend=0.458; [underlined: Large artery atherosclerosis,] HR (95% CI); Q1 (ref) vs Q2: 0.97 (0.72, 1.30); Q1 (ref) vs Q3: 0.88 (0.65, 1.19); Q1 (ref) vs Q4: 0.69 (0.50, 0.95); P-trend=0.020; [underlined: Cardioembolism,] HR (95% CI); Q1 (ref) vs Q2: 1.36 (0.69, 2.66); Q1 (ref) vs Q3: 1.49 (0.78, 2.88); Q1 (ref) vs Q4: 2.50 (1.38, 4.53); P-trend=0.001; [underlined: Small vessel occlusion,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend=0.518; EPA; [underlined: Total ischemic stroke,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend=0.732; [underlined: Large artery atherosclerosis,] HR (95% CI); Q1 (ref) vs Q2: 0.86 (0.64, 1.16); Q1 (ref) vs Q3: 0.82 (0.60, 1.11); Q1 (ref) vs Q4: 0.66 (0.48, 0.91); P-trend=0.012; [underlined: Cardioembolism,] HR (95% CI); Q1 (ref) vs Q2: 1.17 (0.58, 2.35); Q1 (ref) vs Q3: 2.34 (1.27, 4.30); Q1 (ref) vs Q4: 2.02 (1.09, 3.73); P-trend=0.005; [underlined: Small vessel occlusion,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend=0.647; Results of analyses for other subtypes (stroke of other cause, stroke of undetermined cause) were NS for all exposures. See Veno, 2019 for more details.; DPA; [underlined: Total ischemic stroke,] HR (95% CI); Q1 (ref) vs Q2: 1.10 (0.96, 1.26); Q1 (ref) vs Q3: 1.10 (0.96, 1.26); Q1 (ref) vs Q4: 1.16 (1.02, 1.33); P-trend=0.033; [underlined: Large artery atherosclerosis,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend=0.353; [underlined: Cardioembolism,] HR (95% CI); Q1 (ref) vs Q2: 0.80 (0.41, 1.56); Q1 (ref) vs Q3: 1.14 (0.63, 2.08); Q1 (ref) vs Q4: 1.68 (0.96, 2.91); P-trend=0.020; [underlined: Small vessel occlusion,] HR (95% CI); Q1 (ref) vs Q2: 1.27 (1.04, 1.55); Q1 (ref) vs Q3: 1.21 (0.99, 1.48); Q1 (ref) vs Q4: 1.19 (0.98, 1.46); P-trend=0.179; DHA; [underlined: Total ischemic stroke,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend=0.513; [underlined: Large artery atherosclerosis,] HR (95% CI); Q1 (ref) vs Q2: 0.90 (0.67, 1.22); Q1 (ref) vs Q3: 0.86 (0.63, 1.16); Q1 (ref) vs Q4: 0.72 (0.53, 0.99); P-trend=0.043; [underlined: Cardioembolism,] HR (95% CI); Q1 (ref) vs Q2: 0.97 (0.50, 1.89); Q1 (ref) vs Q3: 1.27 (0.68, 2.36); Q1 (ref) vs Q4: 2.12 (1.21, 3.69); P-trend=0.002; [underlined: Small vessel occlusion,] HR (95% CI); Q1 (ref) vs Q2: 1.26 (1.04, 1.54); Q1 (ref) vs Q3: 1.17 (0.96, 1.43); Q1 (ref) vs Q4: 1.13 (0.93, 1.38); P-trend=0.411; Results of analyses for other subtypes (stroke of other cause, stroke of undetermined cause) were NS for all exposures. See Veno, 2019 for more details. | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (length of education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: WC (adjusted for BMI).; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; The Danish Heart Foundation; The Danish Cancer Society
Praagman, 2019 (https://pubmed.ncbi.nlm.nih.gov/30482628/) ^198^; PCS, DDCH (Danish Diet, Cancer and Health; EPIC-Denmark) and EPIC-Norfolk, Denmark and U.K.; Baseline N=82,692 Analytic N=75,425 (Attrition: 9%); Participant characteristics at baseline:; - Participants without history of cancer, CVD or MI; - Age: Mean~58 y; - Sex (female): ~54%; - Race/ethnicity: NR; - SES: EPIC-Norfolk: Educational level: None ~36%, Degree ~13%; EPIC-Denmark: 7y or less: ~33%, 8-10y ~46%, >10y ~21%; - Anthropometry: BMI, Mean~26.2; Fat intake at baseline, Mean (SD):; - SFAs: Norfolk: 13.3%E (3.5); Denmark: 12.5%E (2.6); - MUFAs: Norfolk: ~9.3%; Denmark: ~11.0%E; - PUFAs: Norfolk: ~5.8%E; Denmark: ~5.4%E; - Cholesterol: Norfolk: ~277 mg; Denmark: ~443mg; Blood lipids and BP at baseline, Mean:; - TC: Norfolk: ~6.2 mmol/L; - HDL: Norfolk: ~1.4 mmol/L; - LDL: Norfolk: ~4.0 mmol/L; - Triglycerides: Norfolk: ~1.8 mmol/L; - SBP: Norfolk: ~135 mmHg; Denmark: ~140 mmHg; - DBP: ~83 mmHg; Summary of findings:; In Denmark, higher intake of SFAs from meat was significantly associated with higher risk of MI incidence; higher intake of SFAs (C4:0-C10:0) was significantly associated with lower risk of MI. Additionally, replacing 1%E of SFA (C12:0-C18:0) with 1%E plant protein was significantly associated with lower risk of MI. | Exposures:; - SFAs (quintiles); - Sum of C4:0-C10:0 (Median intake for Norfolk and Denmark, respectively); - Q1: 0.3; 0.6; - Q2: 0.5; 0.95; - Q3: 0.7; 1.23; - Q4: 1.0; 1.54; - Q5: 1.6; 2.05; - Sum of C12:0-C18:0 (Median intake for Norfolk and Denmark, respectively); - Q1: 8.4; 9.3; - Q2: 10.5; 10.5; - Q3: 11.9; 12.5; - Q4: 13.5; 13.7; - Q5: 16.2; 15.4; - Specific sources of SFAs (continuous, per 1%E) from (Median):; - Total dairy (Norfolk: 3.7%E; Denmark: 4.1%E); - Meat (Norfolk: 1.6%E; Denmark: 3.2%E); - Cakes & cookies (Norfolk: 1.5%E); - Cheese (Norfolk: 1.1%E); - Soft fats (Norfolk: 0.8%E); - Hard fats (Norfolk: 0.04%E); - Replacement of 1%E/d of SFAs (continuous) with 1%E of:; - CisMUFA; - CisPUFA; - Starch carbohydrates; - Plant protein; [underlined: Assessment method and timing]:; - Self-administered, validated FFQ to assess intake in the previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 18.8y (Norfolk) and 13.6y (Denmark) of follow-up; - [underlined: Incidence myocardial infarction:] death certification at United Kingdom Office of National Statistics, The Danish National Patient Register, The Danish Register of Causes of Death, Norfolk Health Authority database, Danish National Patient Register; - [underlined: MI cases:] 1,204 in Norfolk, 2,260 in Denmark | [underlined: Incident MI,] HR (95% CI); Sum of C4:0-C10:0*; [underlined: Norfolk:] Q1 vs Q2, Q3, Q4, Q5: All NS; P-trend=NS; [underlined: Denmark:] Q1 vs Q2, Q5: NS; Q1 vs Q3: 0.87 (0.75, 1.00), P<0.05; Q1 vs Q4: 0.81 (0.69, 0.94), P<0.05; P-trend: NS; [underlined: Pooled]; Q1 vs Q2, Q3, Q5: NS; Q1 vs Q4: 0.82 (0.72, 0.93); Sum of C12:0-C18:0*; [underlined: Norfolk:] Q1 vs Q2, Q3, Q4, Q5: All NS; P-trend=NS; [underlined: Denmark:] Q1 vs Q2, Q3, Q4, Q5: All NS; P-trend=NS; [underlined: Pooled:] Q1 vs Q2, Q3, Q4, Q5: All NS; *Additional adjustment for hypercholesterolemia and menopausal status did not change results; Specific sources of SFAs from:; [underlined: Norfolk:]; Total dairy (not incl butter): NS; Meat: NS; Cakes & cookies: NS; Cheese: NS; Soft fats: NS Hard fats: NS; [underlined: Denmark:]; Total dairy: NS; Meat: 1.08 (1.04, 1.12), P<0.05; Replacement of sum C12:0-C18:0 with:; [underlined: Norfolk:]; cisMUFA: NS; cisPUFA: NS; Starch carbohydrates: NS; Plant protein: NS; [underlined: Denmark:]; cisMUFA: NS; cisPUFA: NS; Starch carbohydrates: NS; Plant protein: 0.87 (0.82, 0.94) | Key confounders [underlined: NOT] accounted for:; Race/ethnicity; Key confounders accounted for: Sex, age, SES (education level), TEI, alcohol intake, physical activity, smoking, family history of CVD (EPIC-Norfolk only); Additional model adjustments: BMI, hypertension, use of post-menopausal hormones, sum of other SFAs, intake of protein and PUFA EPIC-Norfolk only: aspirin use, multivitamin use, and trans-fatty acids; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Cancer Research U.K.; Medical Research Council; MRC; Danish Cancer Society
Strom, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22146511) ^208^; PCS, Danish National Birth Cohort, Denmark; Baseline N=53,981, Analytic N=48,627 (Attrition: ~10%); Participant characteristics at baseline:; - Pregnant women at ~25 weeks gestation without preeclampsia or gestational diabetes; - Age: Mean=29.9y (range: 15.7-46.9y); - Sex (female): 100%; - Race/ethnicity: NR; - SES: Education, 24% ≤10y school, 51% high school, 25% unknown; Occupation, 39% white collar, 19% skilled, 21% unskilled, 12% student, 10% unemployed; - Anthropometry: Pre-pregnant BMI, 4% <18.5, 69% ≥18.5-25.0, 19% ≥25.0-30.0, 7% ≥30.0; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - NR; Summary of findings:; Among women interviewed when pregnant, higher intake of long chain n-3 PUFA at ~30y of age was associated with lower risk of incident cerebrovascular disease and ischemic heart disease during ~8y of follow-up. | Exposures:; - Marine long chain n-3 PUFA (lowest intake and quintiles; energy-adjusted g/d), Median:; - Lowest 3% (n=1446): 0.06; - Q1 (n=9227): 0.13; - Q2 (n=9521): 0.21; - Q3 (n=9517): 0.31; - Q4 (n=9509): 0.45; - Q5 (ref; n=9407): 0.73; [underlined: Assessment method and timing]:; - Self-administered, validated, semi-quantitative >360-item FFQ representing intake during previous 1mo (n-3 PUFA quantified based on estimated fish intake); - Assessed at baseline (~25wk gestation); Outcomes and assessment methods:; - Assessed during ~8y (range: 6-12y) of follow-up; - [underlined: Incident CVD:] Obtained via linkage with Danish National Patient Registry; Included cerebrovascular diseases and ischemic heart diseases; - [underlined: Cerebrovascular disease:] 146 cases; - [underlined: Ischemic heart disease:] 103 cases; - [underlined: Note:] (328 cases of hypertensive disease, not an included outcome) | Marine long chain n-3 PUFA; [underlined: Incident Cerebrovascular Disease,] HR (95% CI); Q5 (ref) vs Lowest 3%: 2.34 (1.10, 4.99); Q5 (ref) vs Q1, Q2, Q3, or Q4: Data NR; [underlined: Incident Ischemic Heart Disease,] HR (95% CI); Q5 (ref) vs Lowest 3%: 3.80 (1.53, 9.42); Q5 (ref) vs Q1, Q2, Q3, or Q4: Data NR | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (education, occupation), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: Prepregnant BMI, cohabitant status, parity, SFA intake, fiber intake, trans-FA intake; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of women with preeclampsia or gestational diabetes; - No preregistered statistical analysis plan; Funding sources:; Faroese Research Council; Fisheries Research Fund of the Faroe Islands; EU Sixth Framework Programme Integrated Research Project SEAFOOD-plus; EU Sixth Framework Programme EARNEST; Nordic Working Group on Fishery Research
Bendinelli, 2011 (https://pubmed.ncbi.nlm.nih.gov/21177799/) ^143^; PCS, EPIC-Italy, Italy; Baseline N=32,578 Analytic N=29,689 (Attrition: 9%); Participant characteristics at baseline:; - 100% without prevalent stroke or myocardial infarction; - Age: Mean: 50.0 (SE=7.9), range 35-74; - Sex (female): 100%; - Race/ethnicity: NR; - SES: Education: None/elementary school ~29%, Secondary/professional school ~34%, High school ~23%, University degree ~14%; - Anthropometry: BMI~25.7; Fat intake at baseline, Mean:; - Olive oil: 24.7 (SE=13.0) g/d; Blood lipids and BP at baseline: NR; Summary of findings:; Olive oil intake was significantly associated with lower risk of CHD incidence; this was no longer significant among post-menopausal women only. | Exposures:; - Olive oil (continuous, per 10 g; categorical in quartile); - Q1 (ref): ≤15.9g; - Q2: ≤22.5g; - Q3: ≤31.2g; - Q4: >31.2g; [underlined: Assessment method and timing]:; - Self-administered, validated semi-quantitative FFQ to assess usual food intake in previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during mean of 7.85 y of follow-up; - [underlined: Incident CHD (fatal and nonfatal events of myocardial infarction, coronary revascularization, or both); unspecified cardiac event:] Death certificates from Mortality Registries, hospital discharge files; - [underlined: Nonfatal MI:] 144 events; - [underlined: Fatal MI with hospitalization:] 3; - [underlined: Fatal MI without hospitalization:] 9; - [underlined: Coronary revascularizations:] 27 events; - [underlined: Unspecified cardiac event:] 1 event | [underlined: Incident CHD,] HR (95% CI); Olive oil:; Q1 (ref) vs Q2, Q3: All NS; Q1 (ref) vs Q4: 0.56 (0.31, 0.99); P-trend=0.04; Continuous:; Olive oil: NS; Post-menopausal women only:; Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend=0.04 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, SES (educational level), TEI excluding alcohol, alcohol intake, physical activity, smoking; Additional model adjustments: Body height, body weight, WC, hypertension, menopausal status, total meat consumption; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to excluding participants who were being treated for hyperlipidemia and diabetes; - No preregistered statistical analysis plan; Funding sources:; Compagnia di San Paolo; Associazione Italiana per la Ricerca sul Cancro; Programma Integrato Oncologia, Regione Toscana, Ministero della Salute
Pala, 2019 (https://pubmed.ncbi.nlm.nih.gov/31435641/) ^193^; PCS, EPIC-Italy, Italy; Baseline N=47,745 Analytic N=45,009 (Attrition: 6%); Participant characteristics at baseline:; - 100% without prevalent CVD; - Age: Mean: 50.1 (SEM=0.037); - Sex (female): NR; - Race/ethnicity: NR; - SES: Relative index of inequality: 0.50 (SEM=0.001); - Anthropometry: BMI, Mean: 26.0 (SEM=0.019); Fat intake at baseline, Mean (SEM):; - SFA: 31.0 (0.054); - MUFA: 41.7 (0.067); - PUFA: 10.6 (0.020); - Butter: 1.7 (0.014); Blood lipids and BP at baseline: NR; Summary of findings:; Butter intake was not significantly associated with CVD mortality. | Exposures:; - Butter (categorical); - 1: 0g (ref); - 2: >0 to ≤1.4g/d; - 3: >1.4 to 100.1g/d; [underlined: Assessment method and timing]:; - Self-administered, validated FFQ to assess usual food intake in previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 14.9 y of follow-up; - [underlined: CVD mortality]: mortality databases; - [underlined: CVD mortality]: 104 cases (0 intake), 223 cases (>0-1.4g), 132 cases (>1.4-100.1g) | [underlined: CVD mortality]; Butter:; Intake category 1 vs 2, 3: All NS | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, SES, TEI, alcohol intake, physical activity, smoking; Additional model adjustments: Center, weight, height, waist-to-hip ratio, intake of sugar, Italian Mediterranean Index; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Associazione Italiana per la Ricerca sul Cancro
de Goede, 2010 (https://pubmed.ncbi.nlm.nih.gov/20335635/) ^153^; PCS, EPIC-Netherlands (MORGEN), Netherlands; Baseline N=22,654 Analytic N=21,342 (Attrition: 6%); Participant characteristics at baseline:; - 100% without prevalent MI or stroke; - Age: Mean: 42.1 y (SD=11.2); - Sex (female): 55%; - Race/ethnicity: Dutch ethnicity: ~97%; - SES: Education: University or higher vocation training ~22%; - Anthropometry: BMI ~25; Fat intake at baseline, Mean:; - EPA+DHA: 114 (62-195) mg/d; - SFA: ~14.4%E; - PUFA: ~6.8%E; Blood lipids and BP at baseline, Mean:; - TC: ~5.3 mmol/L; - HDL: ~1.4 mmol/L; - SBP: ~120 mmHg; - DBP: ~76 mmHg; Summary of findings:; Higher EPA+DHA intake compared to lower EPA+DHA intake was significantly associated with lower fatal CHD and MI incidence, but not non-fatal MI incidence in Dutch adults, aged 20-65 years. | Exposures:; - EPA+DHA (categorical in quartiles); - Q1 (ref, n=5336): Median=40 mg/d; - Q2 (n=5335): Median=84 mg; - Q3 (n=5335): Median=151 mg; - Q4 (n=5336): Median=234 mg; [underlined: Assessment method and timing]:; - Self-administered, validated 178-item FFQ to assess usual intake in the previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during mean of 11.3 y (range 9-14 y) of follow-up; - [underlined: CHD (fatal), MI (fatal or nonfatal):] registries, including Statistics Netherlands, hospital admission data; - [underlined: CHD:] 82 cases; - [underlined: Fatal MI:] 64 cases; - [underlined: Nonfatal MI:] 252 cases | [underlined: Fatal CHD], HR (95% CI); EPA+DHA; Q1 vs Q2, Q3: All NS; Q1 vs Q4: 0.51 (0.27-0.94); P-trend=0.05; [underlined: Fatal MI], HR (95% CI); EPA+DHA; Q1 vs Q2, Q3: All NS; Q1 vs Q4: 0.38 (0.19, 0.77); P-trend=0.01; [underlined: Incident Non-fatal MI], HR (95% CI); EPA+DHA; Q1 vs Q2, Q3, Q4: All NS; P-trend=0.18 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity; Key confounders accounted for: Sex, age, SES (education), TEI, alcohol intake, physical activity, smoking, family history of CHD; Additional model adjustments: BMI, vitamin or mineral supplement use, use of drugs for hypertension or hypercholesterolemia, fruit consumption, vegetable consumption, saturated fat intake; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Ministry of Health, Welfare and Sport of the Netherlands (The Hague); National Institute for Public Health and the Environment (Biilthoven, The Netherlands)
de Goede, 2011 (https://pubmed.ncbi.nlm.nih.gov/21464993/) ^155^; PCS, EPIC-Netherlands (MORGEN), Netherlands; Baseline N=22,654 Analytic N=20,069 (Attrition: 11%); Participant characteristics at baseline:; - 100% without prevalent CVD; - Age: Mean: 41.5 (SD=11.1); - Sex (female): 65%; - Race/ethnicity: NR; - SES: High educational level (higher vocational education and university), ~25%; - Anthropometry: BMI, Mean~24.8; Fat intake at baseline, Mean (SD):; - SFA: ~37 g/d; ~14%E; - Cis-MUFA: ~31 g/d; ~12%E; - PUFA: ~17 g/d; ~7%E; - ALA: ~1.4 g/d; ~0.5%E; Blood lipids and BP at baseline:; - TC: ~5.3 mmol/L; - HDL: ~1.4 mmol/L; - SBP: ~120 mmHg; - DBP: ~76 mmHg; Summary of findings:; ALA intake, especially ALA from salad dressing, was significantly associated with lower odds of total stroke and ischemic stroke. ALA intake, regardless of source, was not associated with risk of CHD. ALA intake from other sources than salad dressing was not associated with total stroke and ischemic stroke. | Exposures:; - ALA (n=19,896; quintiles, g/d); - Total ALA, Median (ALA from salad dressing; ALA from all sources except salad dressing); - Q1 (ref): 1.0 g/d (0.1 g/d; 0.7 g/d); - Q2: 1.2 g/d (0.2 g/d; 0.9 g/d); - Q3: 1.3 g/d (0.3 g/d; 1.0 g/d); - Q4: 1.5 g/d (0.5 g/d; 1.1 g/d); - Q5: 1.9 g/d (0.7 g/d; 1.4 g/d); - ALA from salad dressing; - ALA from other sources than salad dressing; [underlined: Assessment method and timing]:; - Self-administered, validated 178-item FFQ to assess usual food intake in previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 12.2 y of follow-up; - [underlined: Incident CHD and stroke:] Dutch Center for Health Care Information, hospital discharge diagnoses by National Medical Registry; - [underlined: CHD:] 280 cases; - [underlined: Ischemic cerebrovascular accident:] 80 cases; - [underlined: Transient ischemic attacks: 59 cases]; - [underlined: Hemorrhagic stroke:] 47 cases; - [underlined: Unspecified stroke:] 35 cases | [underlined: Incident CHD,] HR (95% CI); ALA intake:; Q1 vs Q2, Q3, Q4, Q5: All NS; ALA intake from salad dressing:; Q1 vs Q2, Q3, Q4, Q5: All NS; ALA intake from other sources than salad dressing: Q1 vs Q2, Q3, Q4, Q5: All NS; [underlined: Incident Total stroke,] HR (95% CI); ALA intake:; Q1 vs Q2: 0.65 (0.43, 0.97); Q1 vs Q3: 0.49 (0.31, 0.76); Q1 vs Q4: 0.53 (0.34, 0.83); Q5: NS; ALA intake from salad dressing:; Q1 vs Q2: NS; Q1 vs Q3: 0.45 (0.29, 0.72); Q1 vs Q4: 0.44 (0.27,0.72); Q1 vs Q5: 0.57 (0.34, 0.96); ALA intake from other sources than salad dressing: Q1 vs Q2, Q3, Q4, Q5: All NS; [underlined: Incident Ischemic Stroke,] HR (95% CI); ALA intake:; Q1 vs Q2: NS; Q1 vs Q3: 0.45 (0.26, 0.79); Q1 vs Q4: 0.56 (0.32, 0.97); Q1 vs Q5: NS; ALA intake from salad dressing:; Q1 vs Q2: NS; Q1 vs Q3: 0.50 (0.29, 0.86); Q1 vs Q4: 0.47 (0.26, 0.86); Q1 vs Q5: NS; ALA intake from other sources than salad dressing: Q1 vs Q2, Q3, Q4, Q5: All NS; Adjustment for plasma cholesterol or SBP did not change results. Associations in subgroups (age and gender) did not differ. | Key confounders [underlined: NOT] accounted for:; Race/ethnicity; Key confounders accounted for: Sex, age, SES (educational level), TEI, alcohol intake, physical activity, smoking, family history of myocardial infarction; Additional model adjustments: BMI, intake of vitamin C, betacarotene, fiber, saturated fatty acids, trans fatty acids, PUFA other than ALA, raw vegetables (only salad dressing and ALA from other sources than salad dressing); Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of participants on lipid or BP medication or with diabetes; - No preregistered statistical analysis plan; Funding sources:; Alpro Foundation, Belgium; Ministry of Health; Welfare and Spot of The Netherlands; National Institute for Public Health, Environment, Bilthoven, The Netherlands; Europe Against Cancer Program of the European Union
de Goede, 2012 (https://pubmed.ncbi.nlm.nih.gov/21816117/) ^154^; PCS, EPIC-Netherlands (MORGEN), Netherlands; Baseline N=22,654 Analytic N=20,069 (Attrition: 11%); Participant characteristics at baseline:; - 100% without prevalent MI or stroke; - Age: Mean: 41.5 y (SD=11.1); - Sex (female): 55%; - Race/ethnicity: Dutch ethnicity: ~97%, previously reported; - SES: Highly educated (University or higher vocation training) ~25%; - Anthropometry: BMI ~25; Fat intake at baseline, Mean (SD):; - LA: 13.9 g/d (5.9); - PUFA intake: LA was 79% of total PUFA intake; Blood lipids and BP at baseline, Mean:; - TC: ~5.3 mmol/L; - HDL: ~1.4 mmol/L; - SBP: ~120 mmHg; - DBP: ~76 mmHg; Summary of findings:; LA was not significantly associated with CHD incidence in Dutch adults ages 20-65 years. | Exposures:; - LA (categorical in quintiles; continuous per 2%E); - Q1 (ref, n=4013): Median=3.7%E; - Q2 (n=4014): Median=4.7%E; - Q3 (n=4014): Median=5.4%E; - Q4 (n=4014): Median=6.2%E; - Q5 (n=4014): Median=7.7%E; [underlined: Assessment method and timing]:; - Self-administered, validated 178-item FFQ to assess usual intake in the previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during median of 10.5 y (range 8-13 y) of follow-up; - [underlined: CHD (fatal CHD, fatal and non-fatal cardiac arrest, nonfatal MI):] registries, including Statistics Netherlands, national hospital discharge register; - [underlined: CHD:] 280 total cases | [underlined: Incident CHD], HR (95% CI); LA; Q1 vs Q2, Q3, Q4, Q5: All NS; Continuous: NS | Key confounders [underlined: NOT] accounted for:; Race/ethnicity; Key confounders accounted for: Sex, age, SES (education), TEI, alcohol intake, physical activity (subgroup), smoking, family history of MI; Additional model adjustments: BMI, dietary fiber, protein, SFA, cis-MUFA, trans fatty acids, PUFA other than LA; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to excluding participants on lipid modifying drugs, antihypertension drugs and diabetes; - No preregistered statistical analysis plan; Funding sources:; Product Board for Margarine, Fats and Oils, Rijswijk, The Netherlands; Wageningen University
Praagman, 2016 (https://pubmed.ncbi.nlm.nih.gov/26791181/) ^196^; PCS, EPIC-Netherlands (MORGEN and Prospect), Netherlands; Baseline N=40,011 Analytic N=35,597 (Attrition: 11%); Participant characteristics at baseline:; - 100% without prevalent CVD; - Age: Mean~49.3 y; - Sex (female): ~75%; - Race/ethnicity: NR; - SES: High educational level, ~20%; - Anthropometry: BMI, Mean~25.7; Fat intake at baseline, Mean:; - Total SFAs: ~34 g/d; Median~14.9%E; - Total PUFAs: ~6.8 %E; - cis MUFAs: ~9.6%E; Blood lipids, BP at baseline, Mean:; - TC: ~5.7 mmol/L; - HDL: ~1.4 mmol/L; - SBP: Mean~126 mmHg; - DBP: Mean~78 mmHg; Summary of findings:; Higher SFA intake at ~49y of age was significantly associated with a lower risk of IHD during ~12.2y of follow-up. Higher intake of SFAs from butter, cheese, milk and milk products were significantly associated with lower risk of IHD. Other foods were not significantly associated with risk of IHD. Replacement of 5%E of SFAs with CHO, cis-MUFAs, PUFAs, protein and animal protein was significantly associated with greater risk of IHD. | Exposures:; - Total SFAs (continuous; per 5% energy); - SFAs (continuous) from:; - Butter (per 1.42% energy); - Cheese (per 1.95% energy); - Milk & milk products (per 1.45% energy); - Meat (per 1.44% energy); - Cakes (per 0.83% energy); - Snacks (per 0.40% energy); - Hard, solid fats (per 1.25% energy); - Soft, liquid fats (per 0.50% energy); - Other (per 1.06% energy); - Replacement of 5% energy from SFAs (continuous) with 5% energy from:; - CHO; - CHO with low GI; - CHO with medium GI; - CHO with high GI; - cis MUFAs; - PUFAs; - Protein; - Animal protein; - Vegetable protein; [underlined: Assessment method and timing]:; - Self-administered, validated 79-item FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 12.2 y of follow-up; - [underlined: Incident ischemic heart disease (IHD; fatal & nonfatal):] morbidity data from Dutch Center for Health Care Information hospital discharge diagnoses; - [underlined: Total:] 1807 cases (158 fatal) | [underlined: Incident IHD,] HR (95% CI); Total SFAs: 0.83 (0.74, 0.93)*; SFAs from:; Butter: 0.94 (0.90, 0.99); Cheese: 0.91 (0.86, 0.97); Milk & milk products: 0.92 (0.86, 0.97); Meat: 1.00 (0.95, 1.06); Cakes: 0.96 (0.91, 1.02); Snacks: 1.03 (0.97, 1.10); Hard, solid fats: 0.97 (0.91, 1.02); Soft, liquid fats: 0.99 (0.95, 1.04); Other: 0.94 (0.88, 1.01); Replacement of SFAs with:; CHO: 1.23 (1.09, 1.40); CHO with low GI: 1.14 (0.91, 1.43); CHO with medium GI: 1.35 (1.05, 1.73); CHO with high GI: 1.27 (1.03, 1.56); cis MUFAs: 1.30 (1.02, 1.65); PUFAs: 1.35 (1.14, 1.61); Protein: 1.29 (1.08, 1.54); Animal protein: 1.37 (1.14, 1.65); Vegetable protein: 0.81 (0.57, 1.17); *Results similar when adjusted for TC:HDL ratio or SBP. See Praagman, 2016 for details. | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, SES (educational level), TEI, alcohol intake, physical activity, smoking; Additional model adjustments: BMI, WC, energy-adjusted intakes of cholesterol, fiber, and vitamin C, trans fat, vegetable protein, animal protein. SFA from sources: total CHO, cis MUFAs, PUFAs; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; “Europe Against Cancer” Programme of the European Commission; Dutch Ministry of Health, Welfare and Sports; Netherlands Organization for Health Research and Development; World Cancer Research Fund
Vissers, 2019 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6768909/) ^215^; PCS, EPIC-Netherlands (MORGEN and Prospect), Netherlands; Baseline N=40,011 Analytic N=35,767 (Attrition: 11%); Participant characteristics at baseline:; - 100% without prevalent CVD; - Age: Mean~49.2 y; - Sex (female): ~75%; - Race/ethnicity: NR; - SES: High educational level (higher vocational education & university), ~20%; - Anthropometry: BMI, Mean~25.7; Fat intake at baseline, Mean (SD):; - SFAs: 34.4 (12.4) g/d, 14.6 (2.5) %E/d; - Dairy:; - SFAs: 17.9 (9.5) g/d, 7.7 (3.5) %E/d; - MUFAs: ~2.3 g/d; - PUFA: ~0.2 g/d; - Meat:; - SFAs:15.3 (3.5) g/d, 6.5 (3.5) %E/d; - MUFAs: ~3.0 g/d; - PUFAs: ~0.7 g/d; - Cholesterol: ~218 mg/d; Blood lipids and BP at baseline: NR; Summary of findings:; Replacement of SFAs from dairy with SFAs from meat was significantly associated with greater risk of CHD. Increase in SFAs, MUFAs, and PUFAs from meat was significantly associated with a greater incidence of CHD. Increase in SFAs and MUFAs from dairy was associated with a lower incidence of CHD when controlling for energy from protein. | Exposures:; - Replacement of dairy-derived SFA, MUFA, and PUFA (1%E) with meat-derived SFA, MUFA, and PUFA (1%E), respectively (continuous); - SFA from meat (per 1%E); - SFA from dairy (per 1%E); - MUFA from meat (per 1%E); - MUFA from dairy (per 1%E); - PUFA from meat (per 1%E); - PUFA from dairy (per 1%E); [underlined: Assessment method and timing]:; - Self-administered, validated 79-item FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 12.2 y of follow-up; - [underlined: Incident coronary heart disease (CHD; fatal & nonfatal):] Dutch Center for Health Care Information, hospital discharge diagnoses by National Medical Registry | [underlined: Incident CHD,] HR (95% CI); Replacement of SFAs from dairy with: SFAs from meat: 1.08 (1.04, 1.13); Replacement of MUFAs from dairy with: MUFAs from meat: NS; Replacement of PUFAs from dairy with: PUFAs from meat: NS; Continuous:; SFAs from meat: 1.06 (1.03, 1.10)*; SFAs from meat: 1.07 (1.04, 1.11)**; MUFAs from meat: 1.05 (1.03, 1.08)*; MUFAs from meat: 1.06 (1.03, 1.09)**; PUFAs from meat: 1.17 (1.07, 1.28)*; PUFAs from meat: 1.18 (1.07, 1.30)**; SFAs from dairy: 0.97 (0.95, 0.99)*; SFAs from dairy: NS**; MUFAs from dairy: 0.94 (0.91, 0.99)*; MUFAs from dairy: NS**; PUFAs from dairy: NS*; PUFAs from dairy: NS**; *Adjusted with protein (%E); **Adjusted with carbohydrate (%E) | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, SES (educational level), TEI, alcohol intake, physical activity, smoking; Additional model adjustments: WC, energy-adjusted intakes of cholesterol and fiber, intake of protein, carbohydrates and all fatty acids except dairy-derived FA from the substitution of interest, protein or carbohydrate (for non-replacement analyses); Limitations:; - Not all key confounders accounted for; - Potential missing data bias for not statistically accounting for missing data; - No preregistered statistical analysis plan; Funding sources:; “Europe Against Cancer” Programme of the European Commission; Dutch Ministry of Public Health, Welfare and Sports; Netherlands Cancer Registry; LK Research Funds; Dutch Prevention Funds, Dutch ZON; World Cancer Research Fund
Buckland, 2012 (https://pubmed.ncbi.nlm.nih.gov/22648725/) ^150^; PCS, EPIC-Spain, Spain; Baseline N=41,438 Analytic N=40,622 (Attrition: 2%); Participant characteristics at baseline:; - Participants were not all free of disease; - Age: Mean~48 y; - Sex (female): ~62%; - Race/ethnicity: NR; - SES: Education: None ~39%, Primary ~39%, Technical/professional ~8.2%, Secondary ~6.5%, University ~11.5%, Unspecified ~4.7%; - Anthropometry: BMI: <25 ~22%, 25-30: ~48%, ≥30 ~30%; Fat intake at baseline, Mean (SD):; - Olive oil: 20.1 (13.1) g/day per 2000 kcal; Blood lipids and BP at baseline: NR; Summary of findings:; Highest quartiles of olive oil consumption compared to non-consumers was associated with reduced risk of CVD-related mortality. | Exposures:; - Olive oil (continuous, 10 g/d per 2000 kcal; categorical in quartile, g/2000 kcal/d); - Non-consumers (ref); - Quartile 1: <14.8g; - Quartile 2: 14.8 - <21.7g; - Quartile 3: 21.7 - <29.4g; - Quartile 4: ≥29.4g; [underlined: Assessment method and timing]:; - Interview-administered, validated dietary history questionnaire to assess usual food intake in previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during mean of 10.4 (SD=1.3) y of follow-up; - [underlined: CVD deaths:] follow-up, EPIC-Spain database, Spanish National Statistics Institute | [underlined: CVD deaths,] HR (95% CI); Olive oil:; Non-consumers (ref) vs:; Q1: NS; Q2: NS; Q3: 0.71 (0.52, 0.98); Q4: 0.56 (0.40, 0.79); P-trend<0.001; Continuous:; Olive oil: 0.87 (0.80, 0.94) | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, SES (educational level), TEI excluding alcohol, alcohol intake, physical activity, smoking; Additional model adjustments: Center, BMI, WC, fruit, vegetables, dairy, meat; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Spanish Ministry of Health; Spanish Regional Governments of Andalusia, Asturias, Basque Country, Murcia and Navarra; Catalan Institute of Oncology
Buckland, 2012a (https://pubmed.ncbi.nlm.nih.gov/23006416/) ^151^; PCS, EPIC-Spain, Spain; Baseline N=41,438 Analytic N=40,142 (Attrition: 3%); Participant characteristics at baseline:; - 100% without prevalent CHD; - Age: Mean~48 y; - Sex (female): ~62%; - Race/ethnicity: NR; - SES: Education: None ~39%, Primary ~39%, Technical/professional ~8.2%, Secondary ~6.5%, University ~11.5%, Unspecified ~4.7%; - Anthropometry: BMI: <25 ~22%, ≥25 ~78%; Fat intake at baseline, Mean:; - SFAs: ~26.4g; - MUFA: ~37.4g; - PUFA: ~13.7g; - Olive oil: 20.1g/d per 2000 kcal; Blood lipids and BP at baseline: NR; Summary of findings:; Olive oil intake was not significantly associated with risk of CHD. | Exposures:; - Olive oil (continuous, 10 g/d per 2000 kcal; categorical in quartile); ○ Q1 (ref): <10.0g; ○ Q2: 10.0 - <20.1g; ○ Q3: 20.1 - <28.9g; ○ Q4: ≥28.9g; [underlined: Assessment method and timing]:; - Interview-administered, validated dietary history questionnaire to assess usual food intake in previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during mean of 10.4 (SD=1.3) y of follow-up; - [underlined: Incident coronary heart disease (CHD; fatal & nonfatal):] self-reported questionnaires, hospital discharge databases, population-based myocardial infarction registries, and regional and national mortality registries | [underlined: Incident CHD,] HR (95% CI); Olive oil:; Quartile 1 (ref) vs Q2, Q3, Q4, All NS; P-trend: P=0.20; Continuous:; Olive oil: NS; Ordinary olive oil: NS; Virgin olive oil: NS; Results did not change when participants with improbable dietary values were excluded; Results did not change among subjects with hyperlipidemia, hypertension, and diabetes at recruitment | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, SES (educational level), TEI excluding alcohol, alcohol intake, physical activity, smoking; Additional model adjustments: BMI, WC, hyperlipidemia, hypertension and diabetes, Mediterranean diet score (excluding olive oil and alcohol); Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Spanish Ministry of Health; Spanish Regional Governments of Andalusia, Asturias, Basque Country, Murcia and Navarra; Catalan Institute of Oncology
Amiano, 2014 (https://pubmed.ncbi.nlm.nih.gov/24360762/) ^138^; PCS, EPIC-Spain, Spain; Baseline N=41,438 Analytic N=41,091 (Attrition: 1%); Participant characteristics at baseline:; - 100% without prevalent CHD; - Age: Mean: 49.2y, SD=8.0; - Sex (female): ~62%; - Race/ethnicity: NR; - SES: Education: None 30.4%, Primary ~38.7%, Technical/professional 8.2%, Secondary 6.5%, University 11.5%, Unspecified 4.7%; - Anthropometry: BMI: underweight 0.7%, normal weight 21.5%, overweight 47.8%, obese 30.1%; Fat intake at baseline, Mean (SD):; - SFAs (g/d): 26.6 (12.4); - MUFA (g/d): 37.5 (15.7); - PUFA (g/d: 13.8 (7.7); - Total n-3 PUFA (g/d): 1.4 (0.7); - EPA (g/d): 0.2 (0.2); - DHA (g/d): 0.4 (0.3); Blood lipids and BP at baseline: NR; Summary of findings:; Total n-3 fatty acid, EPA or DHA intake were not significantly associated with risk of CHD. | Exposures:; - Total n-3 PUFA (g/d); - Q1: (ref; Men ≤1.19, Women ≤0.85); - Q2: (Men 1.20-1.57, Women 0.86-1.12); - Q3: (Men 1.58-2.04, Women 1.13-1.47); - Q4: (Men ≥2.05, Women ≥1.48); - EPA (g/d); - Q1: (ref; Men ≤0.08, Women ≤0.05); - Q2: (Men 0.09-0.17, Women 0.06-0.10); - Q3: (Men 0.18-0.33, Women 0.11-0.21); - Q4: (Men ≥0.34, Women ≥0.22); - DHA (g/d); - Q1: (ref; Men ≤0.19g, Women ≤0.12g); - Q2: (Men 0.20-0.35g, Women 0.13-0.22g); - Q3: (Men 0.36-0.61g, Women 0.23-0.40g); - Q4: (Men ≥0.62g, Women ≥0.41g); [underlined: Assessment method and timing]:; - Interview-administered, validated dietary history questionnaire to assess usual food intake in previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during mean of 10.4 y of follow-up; - [underlined: Incident coronary heart disease (CHD; fatal & nonfatal):] telephone 3y follow-up, hospital discharge databases, population-based myocardial infarction registries, and regional and national mortality registries | Incident CHD, HR (95% CI); [underlined: Total n-3 PUFA:]; Men:; Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend=0.20; Women:; Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend=0.76; [underlined: EPA:]; Men:; Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend=0.57; Women:; Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend=0.57; [underlined: DHA:]; Men:; Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend=0.50; Women:; Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend=0.82 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, SES (educational level), TEI excluding alcohol, alcohol intake, physical activity, smoking; Additional model adjustments: Center, weight, height, waist/hip ratio, BMI, total fat, SFA, PUFA, MUFA, total protein, total carbohydrates, fruit, vegetables, meat, dairy products, vitamin C, vitamin E, use of antithrombotic and antihemorrhagic agents, CVD drugs, salicylic acid and derivatives, use of hormone replacement therapy, high BP, hyperlipidemia, and diabetes; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Spanish Ministry of Health; CIBERESP; European Commission; participating Regional Governments and International Agency for Research on Cancer
Lin, 2018 (https://pubmed.ncbi.nlm.nih.gov/29903989/) ^184^; PCS, FOS (Framingham Offspring Study), U.S.; Baseline N=4,064 Analytic N=993 (Attrition: 76%); Participant characteristics at baseline:; - 100% either impaired fasting glucose or type 2 diabetes; - 100% without prevalent CVD; - Age: Mean: ~52.7; - Sex (female): ~40%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: WC: ~38 inches; Fat intake at baseline, Mean (SD):; - SFAs (%E*): Low cholesterol tertile: 19.0 (7.2), Moderate cholesterol tertile: 25.6 (8.6); High cholesterol tertile: 33.1 (11.2); *May be mislabeled and may be g/d; Blood lipids and BP at baseline: NR; Summary of findings:; Men in the highest tertile of dietary cholesterol intake had significantly lower risk of CVD compared to the lowest tertile. | Exposures:; - Dietary cholesterol (mg); - Low (n=330): (ref; Men 71.0-225.0, Women 58.7-164.2); - Moderate (n=332): (Men 225.1-324.5, Women 164.3-241.2); - High (n=331): (Men 324.6-1033.3, Women 241.3-582.4); [underlined: Assessment method and timing]:; - 3-d diet records; - Assessed at baseline (from 1984 to 1995); Outcomes and assessment methods:; - Assessed during 20 y of follow-up; - [underlined: Incident cardiovascular disease (CVD; fatal & nonfatal myocardial infarction, coronary heart disease, stroke):] follow-up; - [underlined: CVD events:] 210 cases (150 in men, 60 in women) | [underlined: Incident CVD,] HR (95% CI); [underlined: Dietary cholesterol:]; Low (ref) vs moderate: NS; Low (ref) vs high: 0.61 (0.41, 0.90); Men:; Low (ref) vs moderate: NS; Low (ref) vs high: 0.57 (0.36, 0.91); Women:; Low (ref) vs moderate: NS; Low (ref) vs high: NS | Key confounders [underlined: NOT] accounted for: Race/ethnicity, SES, TEI, alcohol intake, physical activity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, smoking; Additional model adjustments: WC, % of energy from SFA and carbohydrates, and use of lipid-lowering medication; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to excluding participants with type 2 diabetes or impaired fasting glucose; - Potential classification of exposures bias due to undefined midpoint for exposure; - Potential bias due to departures from intended exposures due to not controlling for other types of fats; - Potential missing data bias due to high attrition rate of those who did not complete food diaries; - No information on outcome assessment; - No preregistered statistical analysis plan; Funding sources: National Heart, Lung and Blood Institute’s Framingham Heart Study; Multidisciplinary Training Program in Cardiovascular Epidemiology; American Egg Board/Egg Nutrition Center
O’Neil, 2015 (https://pubmed.ncbi.nlm.nih.gov/26450630/) ^191^; PCS, GOS (Geelong Osteoporosis Study), Australia; Baseline N=1,540 Analytic N=1,363 (Attrition: 11%); Participant characteristics at baseline:; - 100% without prevalent CVD; - Age: Mean: ~56 y; - Sex (female): NR; - Race/ethnicity: NR; - SES: NR; - Anthropometry: WC: ~102 cm; Height: ~176 cm; Fat intake at baseline, Mean:; - SFAs: ~36.6g; - MUFAs: ~31.9g; - PUFAs: ~14.2g; BP at baseline, Mean:; - SBP: ~146 mmHg; - DBP: ~93 mmHg; Summary of findings:; Higher intake of SFA was not associated with odds of CVD incidence. | Exposures:; - SFA; [underlined: Assessment method and timing]:; - Self-administered, 74-item FFQ to assess usual intake in the previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 5 y of follow-up; - [underlined: Incident cardiovascular disease] (CVD; cardiac death, non-fatal myocardial infarction, coronary intervention or percutaneous coronary intervention, coronary artery bypass grafting, amputation or transient ischaemic attack, ischaemic or haemorrhagic stroke): hospital medical records at Barwon Health; - [underlined: CVD:] 76 events | [underlined: Incident CVD,] OR (95% CI); [underlined: SFA:] 1.74 (0.92, 3.26) | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, SES, TEI, alcohol intake, physical activity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, smoking; Additional model adjustments: WC, % of energy from SFA and carbohydrates, and use of lipid-lowering medication; Limitations:; - Not all key confounders accounted for; - Potential bias in classification of exposure due to FFQ not being validated; - Analyses did not account for co-exposure (other types of fats); - No preregistered statistical analysis plan; Funding sources:; National Health and Medical Research Council; Cancer Training Branch of the National Cancer Institute
Vedtofte, 2011 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4301411/) ^210^; PCS, GPS (Glostrup Population Studies), Denmark; Baseline N=3,427 Analytic N=3,277 (Attrition: 4%); Participant characteristics at baseline:; - 100% without prevalent IHD; - Age: Mean: ~50.6; - Sex (female): 50%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI~24; Fat intake at baseline, Median:; - ALA: Women 1.2g/d, Men 1.6g/d; - n-3 long chain PUFA (EPA+DHA): Women 0.28 g/d; Men 0.38 g/d; - LA: Women 8.38 g/d; Men 10.9 g/d; BP at baseline, Mean:; - SBP: ~123 mmHg; Summary of findings:; High n-3 long chain PUFA intake compared to low n-3 long chain PUFA intake was significantly associated with lower IHD incidence. ALA and LA intake was not significantly associated with IHD incidence. | Exposures:; - ALA (g/d, Median); - Low (ref; Women 0.81 g/d, Men 1.09 g/d); - Medium (Women 1.24 g/d, Men 1.61 g/d); - High (Women 1.83 g/d, Men 2.27 g/d); - n-3 long chain PUFA; - LA; [underlined: Assessment method and timing]:; - Self-administered, validated 7-d weighed food record; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during median of 23.3 y of follow-up; - [underlined: Incident Ischemic Heart Disease (IHD):] hospital medical records at Barwon Health; - [underlined: IHD:] 471 cases | [underlined: Incident IHD,] HR (95% CI); ALA; [underlined: Women:] Low (ref) vs medium, high: All NS; P-trend: NS; [underlined: Men:] Low (ref) vs medium, high: All NS; P-trend: NS; n-3 long chain PUFA; [underlined: Women:] Low (ref) vs medium: NS; Low (ref) vs high: 0.62 (0.40, 0.97); P-trend=0.04; [underlined: Men:] Low (ref) vs medium, high: All NS; P-trend: NS; LA; [underlined: Women:] Low (ref) vs medium, high: All NS; P-trend: NS; [underlined: Men:] Low (ref) vs medium, high: All NS; P-trend: NS | Key confounders [underlined: NOT] accounted for:; Race/ethnicity; Key confounders accounted for: Sex, age, SES (education), TEI, alcohol intake, physical activity, smoking, family history of acute MI; Additional model adjustments: BMI, SBP, other PUFAs as appropriate (i.e., n-3 LC-PUFA and LA in analyses of ALA; ALA and LA in analyses of n-3 long chain PUFA; ALA and n-3 long chain PUFA in analyses of LA); Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Danish Council for Strategic Research
Stefler, 2017 (https://pubmed.ncbi.nlm.nih.gov/26578528/) ^207^; PCS, HAPIEE (Health Alcohol and Psychosocial Factors in Eastern Europe), Poland, Russia, and Czech Republic; Baseline N=28,945 Analytic N=19,333 (Attrition: 33%); Participant characteristics at baseline:; - 100% without prevalent CVD or diabetes; - Age: ~57 y; - Sex (female): 55%; - Race/ethnicity: Czech (~30%), Polish (~33%), Russian (~37%); - SES: Education: Primary or less ~10%, University ~26%; - Anthropometry: BMI ~27; Fat intake at baseline:; - Olive Oil usage during cooking (1 point for used for cooking): Males: 16.4%, Females 15.1%; Blood lipids and BP at baseline, Mean:; - TC: ~6.0 mmol/L; - Arterial pressure: ~105 mmHg; - Hypertension: ~46%; - Hypercholesterolemia: ~76%; Summary of findings:; Olive oil usage was not significantly associated with CVD, CHD and stroke mortality. | Exposures:; - Olive oil (dichotomous; 1=used olive oil for cooking, 0=not used for cooking); [underlined: Assessment method and timing]:; - Self-administered, semi-quantitative, validated FFQ (136-148 food items); - Assessed at baseline; Outcomes and assessment methods:; - Assessed during a median of 7 y of follow-up; - [underlined: CVD, CHD and stroke mortality:] regional or national death registers | [underlined: Mortality]; Olive oil usage:; CVD: NS; CHD: NS; Stroke: NS | Key confounders [underlined: NOT] accounted for: family history of CVD or diabetes; Key confounders accounted for: Sex, age, race/ethnicity (cohort by country), SES (education), TEI, alcohol intake, physical activity, smoking; Additional model adjustments: Cohort, marital status, vitamin supplement intake; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to excluding participants with diabetes; - Potential bias due to classification of exposures due to exposure not being clearly defined; - No preregistered statistical analysis plan; Funding sources:; Wellcome Trust; U.S. National Institute of Aging; MacArthur Foundation Initiative on Social Upheaval and Health; Russian Scientific Foundation; British Heart Foundation
Houston, 2011 (https://pubmed.ncbi.nlm.nih.gov/20338738/) ^168^; PCS, Health ABC (Healthy, Aging and Body Composition), U.S.; Baseline N=3,075 Analytic N=1,941 (Attrition: 37%); Participant characteristics at baseline:; - 100% without prevalent CVD; - Age: Mean: 74.5 y; - Sex (female): 56%; - Race/ethnicity: 37.8% Black; - SES: Education: <High school education ~22%; - Anthropometry: BMI ~27; Fat intake at baseline, Mean:; - SFA (%E): ~9.6%; - MUFA (%E): ~12.3%; - PUFA (%E): ~8.9%; - Cholesterol (mg/1000kcal): ~110; Blood lipids at baseline, Mean:; - TC: ~5.4 mmol/L; Summary of findings:; SFA, MUFA, PUFA, and cholesterol intake were not significantly associated with CVD incidence. | Exposures:; - SFA (categorical in tertiles, %E); - Tertile 1 (ref): Median=7.2%E; - Tertile 2: Median=9.6%E; - Tertile 3: Median=11.9%E; - MUFA (categorical in tertiles, %E); - Tertile 1 (ref): Median=9.4%E; - Tertile 2: Median=12.2%E; - Tertile 3: Median=15.2%E; - PUFA (categorical in tertiles, %E); - Tertile 1 (ref): Median=6.3%E; - Tertile 2: Median=8.7%E; - Tertile 3: Median=11.4%E; - Cholesterol (categorical in tertiles, mg/1000 kcal); - Tertile 1 (ref): Median=67.3 mg/1000 kcal; - Tertile 2: Median=100.7 mg/1000 kcal; - Tertile 3: Median=147.2 mg/1000 kcal; [underlined: Assessment method and timing]:; - Interviewer-administered, semi-quantitative, validated 108-item FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 9 y of follow-up; - [underlined: Incident CVD (confirmed myocardial infarction, coronary death or stroke):] in-person clinic exams, phone interviews, medical records; - [underlined: CVD events: 203 cases] | [underlined: CVD incidence], HR (95% CI); SFA:; CVD: T1 vs T2, T3, All NS; P-trend: NS; MUFA:; CVD: T1 vs T2, T3, All NS; P-trend: NS; PUFA:; CVD: T1 vs T2, T3, All NS; P-trend: NS; Cholesterol:; CVD: T1 vs T2, T3, All NS; P-trend: NS; [underlined: CVD incidence], HR (95% CI); [underlined: Dietary Cholesterol intake:]; [underlined: Participants with Type 2 Diabetes:]; T1 vs T2: NS; T1 vs T3: 3.66 (1.09, 12.29); P-trend=0.04; [underlined: Participants without diabetes:]; T1 vs T2, T3, All NS; P-trend: NS | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes; Key confounders accounted for: Sex, age, race/ethnicity, SES (education), TEI, alcohol intake, physical activity, smoking; Additional model adjustments: Field center, BMI, protein intake, fiber intake, multivitamin use, supplemental vitamin E use, statin use, aspirin use, oral estrogen use (women only), prevalent diabetes or hypertension, other types of fats (e.g., SFA analyses controlled for MUFA, PUFA, trans fat, and cholesterol); Limitations:; - Not all key confounders accounted for; - Potential bias in classification of exposures due to not validated FFQ; - Potential missing data bias due to not statistically accounting for missing data; - No preregistered statistical analysis plan; Funding sources:; Intramural Research Program of the NIH, National Institute on Aging; National Institute of Aging; Wake Forest University Claude D. Pepper Older Americans Independence Center; American Egg Board/Egg Nutrition Center
Yamagishi, 2010 (https://www.ncbi.nlm.nih.gov/pubmed/20685950) ^222^; PCS, JACC, Japan; Baseline N=110,792, Analytic N=58,453 (Attrition: 47%); Participant characteristics at baseline:; - Men and women 40-79y of age without history of heart disease, stroke, or cancer at baseline; - Age: Mean~56y; - Sex (female): 60.6%; - Race/ethnicity: NR; - SES: College or higher education, ~18% men, ~11% women; - Anthropometry: BMI, Mean~23; Fat intake at baseline:; - SFA: See “Exposures” in next column; - MUFA (g/d): Mean~9.5; - PUFA (g/d): Mean~7.9; Blood lipids and BP at baseline:; - History of hypertension: ~21%; Summary of findings:; In men and women, higher intakes of SFA at ~56y of age was significantly associated lower risk of total stroke mortality, in particular lower risk of intraparenchymal hemorrhage and ischemic stroke mortality, during ~14.1y of follow-up. SFA intake was not associated with IHD, MI, cardiac arrest, or heart failure mortality. Replacement of SFA with PUFA was associated with higher risk of total stroke mortality; replacement of SFA with MUFA or CHO was not associated with total stroke mortality. | Exposures:; - SFA (quintiles; energy adjusted g/d); - Q1 (ref): 2.5 to <11.0; - Q2: 11.0 to <13.4; - Q3: 13.4 to <15.4; - Q4: 15.4 to <17.9; - Q5: 17.9 to 40.0; - Replacement of SFA (continuous; per 1%E substituted) with:; - MUFA; - PUFA; - CHO; [underlined: Assessment method and timing]:; - 33-item FFQ; SFA values divided by underestimation factor (63.3%) derived from comparison with dietary records in subsample (mostly women); - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~14.1y of follow-up; - [underlined: CVD Mortality:] Obtained through death certificates from public health centers; - [underlined: Total CVD Mortality:] 2,142; - [underlined: Total Stroke Mortality:] 976 cases; - [underlined: Intraparenchymal Hemorrhage Mortality:] 224 cases; - [underlined: Subarachnoid Hemorrhage Mortality:] 153 cases; - [underlined: Ischemic Stroke Mortality:] 321 cases; - [underlined: Ischemic Heart Disease (IHD) Mortality:] 420 cases; - [underlined: MI Mortality:] 330 cases; - [underlined: Cardiac Arrest Mortality:] 107 cases; - [underlined: Heart Failure Mortality:] 309 cases | SFA; [underlined: Total CVD Mortality,] HR (95% CI); Q1 (ref) vs Q2: 0.89 (0.78, 1.02); Q1 (ref) vs Q3: 0.89 (0.77, 1.03); Q1 (ref) vs Q4: 0.89 (0.77, 1.04); Q1 (ref) vs Q5: 0.82 (0.69, 0.97); P-trend: 0.05; [underlined: Total Stroke Mortality,] HR (95% CI); Q1 (ref) vs Q2: 0.90 (0.74, 1.09); Q1 (ref) vs Q3: 0.89 (0.72, 1.10); Q1 (ref) vs Q4: 0.80 (0.64, 1.00); Q1 (ref) vs Q5: 0.69 (0.53, 0.89); P-trend: 0.004; [underlined: Intraparenchymal Hemorrhage Mortality,] HR (95% CI); Q1 (ref) vs Q2: 0.87 (0.58, 1.29); Q1 (ref) vs Q3: 0.89 (0.58, 1.36); Q1 (ref) vs Q4: 0.90 (0.57, 1.42); Q1 (ref) vs Q5: 0.48 (0.27, 0.85); P-trend: 0.03; [underlined: Subarachnoid Hemorrhage Mortality,] HR (95% CI); Q1 (ref) vs Q2: 1.77 (1.08, 2.89); Q1 (ref) vs Q3: 1.12 (0.64, 1.98); Q1 (ref) vs Q4: 1.22 (0.68, 2.20); Q1 (ref) vs Q5: 0.91 (0.46, 1.80); P-trend: 0.47; [underlined: Ischemic Stroke Mortality,] HR (95% CI); Q1 (ref) vs Q2: 0.74 (0.53, 1.04); Q1 (ref) vs Q3: 0.79 (0.55, 1.14); Q1 (ref) vs Q4: 0.63 (0.42, 0.93); Q1 (ref) vs Q5: 0.58 (0.37, 0.90); P-trend: 0.01; [underlined: IHD Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.86; [underlined: MI Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.40; [underlined: Cardiac Arrest Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.11; [underlined: Heart Failure Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.83; Replacement of SFA; [underlined: Total Stroke Mortality,] HR (95% CI); With MUFA: 1.06 (0.89, 1.27); With PUFA: 1.19 (1.09, 1.30); With CHO: 1.05 (0.98, 1.13); [underlined: IHD Mortality,] HR (95% CI); With MUFA: 0.95 (0.74, 1.23); With PUFA: 1.02 (0.89, 1.16); With CHO: 1.00 (0.91, 1.11) | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: History of hypertension and diabetes, smoking status, BMI, mental stress, intake of cholesterol, n-3 and n-6 PUFA, vegetables and fruit.; Limitations:; - Not all key confounders accounted for; - FFQ was not validated; - No information on whether those excluded for incomplete dietary data differed from responders; - No preregistered statistical analysis plan; Funding sources:; Grants-in-Aid for Scientific Research from the Ministry of Education, Science, Sports and Culture of Japan and Tokyo
Wakai, 2014 (https://www.ncbi.nlm.nih.gov/pubmed/24597664) ^216^; PCS, JACC, Japan; Baseline N=86,401, Analytic N=58,672 (Attrition: 32%); Participant characteristics at baseline:; - Men and women 40-79y of age without history of MI, stroke, or cancer at baseline; - Age: Mean~56y; - Sex (female): 60.6%; - Race/ethnicity: NR; - SES: College or higher education, ~19% men, ~11% women; - Anthropometry: BMI, Mean~23; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - NR; Summary of findings:; In men, higher intake of PUFA, particularly n-6 PUFA, and a higher PUFA:SFA intake ratio at ~56y of age was significantly associated with CVD mortality during ~19.3y of follow-up; no significant association between these variables and CVD mortality was detected in women. In both men and women, intake of SFA, MUFA, and n-3 PUFA at ~56y of age was not associated with CVD mortality, except for the comparison between the 4^th^ and 1^st^ quartile of intake for SFA. | Exposures:; - SFA (quintiles; %E), Medians:; - Q1: 3 (men), 3.7 (women); - Q2: 4.1 (men), 5.2 (women); - Q3: 4.9 (men), 6.3 (women); - Q4: 5.8 (men), 7.1 (women); - Q5: 7.3 (men), 8.6 (women); - MUFA (quintiles; %E), Medians:; - Q1: 3.3 (men), 4.2 (women); - Q2: 4.3 (men), 5.4 (women); - Q3: 5.0 (men), 6.2 (women); - Q4: 5.9 (men), 7.1 (women); - Q5: 7.4 (men), 8.6 (women); - PUFA (quintiles; %E), Medians:; - Q1: 2.6 (men), 3.2 (women); - Q2: 3.3 (men), 4.0 (women); - Q3: 3.7 (men), 4.4 (women); - Q4: 4.2 (men), 4.8 (women); - Q5: 5.0 (men), 5.5 (women); - n-3 PUFA (quintiles; %E), Medians:; - Q1: 0.5 (men), 0.6 (women); - Q2: 0.6 (men), 0.8 (women); - Q3: 0.8 (men), 0.9 (women); - Q4: 0.9 (men), 1.1 (women); - Q5: 1.2 (men), 1.3 (women); - n-6 PUFA (quintiles; %E), Medians:; - Q1: 2.1 (men), 2.6 (women); - Q2: 2.7 (men), 3.3 (women); - Q3: 3.2 (men), 3.8 (women); - Q4: 3.7 (men), 4.3 (women); - Q5: 4.5 (men), 5.0 (women); - PUFA:SFA ratio (quintiles), Medians:; - Q1: 0.49 (men), 0.48 (women); - Q2: 0.64 (men), 0.61 (women); - Q3: 0.76 (men), 0.71 (women); - Q4: 0.91 (men), 0.85 (women); - Q5: 1.17 (men), 1.12 (women); [underlined: Assessment method and timing]:; - 33-item FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~19.3y of follow-up; - [underlined: CVD Mortality:] Obtained through death certificates from public health centers; Includes CVD, stroke, and CHD mortality.; - [underlined: Total:] 3,393 cases | [underlined: CVD Mortality,] HR (95% CI); SFA; Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.30; Women:; Q1 (ref) vs Q2: 0.97 (0.84, 1.11); Q1 (ref) vs Q3: 1.07 (0.92, 1.23); Q1 (ref) vs Q4: 0.85 (0.72, 0.99); Q1 (ref) vs Q5: 0.99 (0.84, 1.16); P-trend: 0.46; MUFA; Men and Women:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.74 (men), 0.32 (women); PUFA; Men:; Q1 (ref) vs Q2: 1.02 (0.85, 1.22); Q1 (ref) vs Q3: 1.06 (0.89, 1.26); Q1 (ref) vs Q4: 1.10 (0.92, 1.31); Q1 (ref) vs Q5: 1.18 (0.99, 1.41); P-trend: 0.044; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.59; n-3 PUFA; Men and Women:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.36 (men), 0.36 (women); n-6 PUFA; Men:; Q1 (ref) vs Q2: 0.96 (0.80, 1.15); Q1 (ref) vs Q3: 1.14 (0.96, 1.37); Q1 (ref) vs Q4: 1.23 (1.03, 1.47); Q1 (ref) vs Q5: 1.18 (0.98, 1.42); P-trend: 0.015; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.92; PUFA:SFA Ratio; Men:; Q1 (ref) vs Q2: 1.38 (1.15, 1.66); Q1 (ref) vs Q3: 1.29 (1.07, 1.55); Q1 (ref) vs Q4: 1.38 (1.15, 1.66); Q1 (ref) vs Q5: 1.39 (1.16, 1.66); P-trend: 0.011; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.48 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: Area, BMI, sleep duration, consumption of vegetables and fruit.; Limitations:; - Not all key confounders accounted for; - Analyses did not account for co-exposures (other FAs); - No information on whether those excluded for incomplete dietary data differed from responders; - No preregistered statistical analysis plan; Funding sources:; Grants-in-Aid for Scientific Research from the Ministry of Education, Science, Sports and Culture of Japan and Tokyo
Yamagishi, 2013 (https://www.ncbi.nlm.nih.gov/pubmed/23404536) ^221^; PCS, JPHC, Japan; Baseline N=92,905, Analytic N=81,932 (Attrition: 12%); Participant characteristics at baseline:; - No history of CVD or cancer; - Type 2 diabetes (%): ~3.3; - Age: Mean=56.7; - Sex (female): 53.5%; - Race/ethnicity: NR; - SES: ~7% non-employed; - Anthropometry: BMI, Mean~23.6; Fat intake at baseline:; - SFA (g/d): Median=16.3; - MUFA (g/d): Mean~22; Blood lipids and BP at baseline, Mean:; - TC (mg/dL): ~207; - SBP (mmHg): ~130; - DBP (mmHg): ~78; - Hypertension (%): ~19; Summary of findings:; Dietary saturated fat intake was inversely, statistically associated with incidence rates of total stroke, and total CVD, and positively associated with incidence rates of myocardial infarction (in men, not women) during 11y follow-up. No significant association was seen between saturated fat intake and incidence rates of ischemic stroke and sudden cardiac death over the same period. | Exposures:; - SFA intake (quintiles, g), Median; - Q1 9.6; - Q2 13.4; - Q3 16.3; - Q4 19.4; - Q5 24.9; [underlined: Diet assessment method and timing]:; - 138-item FFQ (validated); - Administered at ~5y after baseline; Outcomes and assessment methods:; - Assessed during mean 11.1y (median=9.9y) of follow-up; - [underlined: Total CVD] ascertained by record linkage to medical and death registers.; - [underlined: Total stroke]: 3192 cases; - [underlined: Ischemic stroke]: 1939 cases; - [underlined: Myocardial infarction:] 610 cases; - [underlined: Sudden cardiac death]: 116 cases | SFA; [underlined: Total stroke,] HR (95% CI); Q1 (ref) vs Q2: 0.98 (0.88–1.10); Q1 (ref) vs Q3: 0.90 (0.79–1.03); Q1 (ref) vs Q4: 0.83 (0.71–0.97); Q1 (ref) vs Q5: 0.77 (0.65–0.93); P=0.002; [underlined: Ischemic stroke,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4 or Q5: All NS; P=0.08; [underlined: Myocardial infarction,] HR (95% CI); Q1 (ref) vs Q2: 0.90 (0.68–1.18); Q1 (ref) vs Q3: 1.24 (0.92–1.67); Q1 (ref) vs Q4: 1.24 (0.88–1.75); Q1 (ref) vs Q5: 1.39 (0.93–2.08); P=0.046; [underlined: Sudden cardiac death,] HR (95% CI); Q1 (ref) vs Q2: 0.53 (0.30–0.93); Q1 (ref) vs Q3: 0.29 (0.14–0.60); Q1 (ref) vs Q4: 0.42 (0.19–0.92); Q1 (ref) vs Q5: 0.39 (0.15–0.99); P=0.06; [underlined: Total CVD,] HR (95% CI); Q1 (ref) vs Q2: 0.94 (0.85–1.05)); Q1 (ref) vs Q3: 0.91 (0.81–1.03); Q1 (ref) vs Q4: 0.86 (0.75–0.98); Q1 (ref) vs Q5: 0.82 (0.69–0.96); P=0.01; Secondary analysis by sex indicated the positive association between SFA intake and incidence of myocardial infarction was significant in men but not in women. | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, SES, family history of CVD or diabetes; Key confounders accounted for: Age, sex, TEI, smoking, alcohol intake, physical activity; Additional model adjustments: Cohort, perceived mental stress, energy-adjusted intakes of carbohydrates, protein, cholesterol, vegetables, fruit and calcium; Limitations:; - Not all key confounders accounted for and assessment occurred 5y prior to dietary intake assessment; - Analyses did not account for co-exposures (e.g. MUFA, PUFA); - No preregistered statistical analysis plan; Funding sources:; Ministry of Health, Labour and Welfare of Japan; Ministry of Education, Culture, Sports, Science, and Technology of Japan.
Virtanen, 2014 (https://www.ncbi.nlm.nih.gov/pubmed/25256234) ^213^; PCS, KIHD (Kuopio Ischaemic Heart Disease Risk Factor Study), Finland; Baseline N=2,682, Analytic N=1,981 (Attrition: 62%); Participant characteristics at baseline:; - Men, aged 42-60 years with no history of stroke or coronary artery disease; - Age: Mean=52y, SD=5.3; - Sex (female): 0%; - Race/ethnicity: NR; - SES: Education (years): Mean=9, SD=3.6; - Anthropometry: BMI, Mean= 26.7, SD=3.5; Fat intake at baseline, Mean (SD):; - SFAs (%E): 18.0 (4.1); - MUFAs (%E): 11.0 (2.2); - PUFAs (%E): 4.6 (1.5; - n-3 PUFA (%E): 0.7 (0.3); Blood lipids and BP at baseline, Mean (SD):; - LDL (mmol/L): 4.00 (0.99); - HDL (mmol/L): 1.31 (0.29); - Triglycerides (mmol/L): 1.25 (0.74); - Hypertension: 56%; Summary of findings:; Increased intake of polyunsaturated fat is associated with fatal, but not non-fatal CHD and an isocaloric replacement of saturated fat or carbohydrate with polyunsaturated fat is associated with reduced risk of fatal and non-fatal CHD in middle-aged and older men from eastern Finland. An isocaloric substitution of SFA with monounsaturated fat increased CHD risk. No association was found between saturated fat and fatal and non-fatal CHD. | Exposures:; - Type dietary fat: yearly updated totals; - SFA (quintiles; Range, %E); - Q1 (ref; < 15.2); - Q2 (15.2-17.7); - Q3 (17.8-20.6); - Q4 (>20.6); - MUFA (quintiles; Range, %E); - Q1 (ref; < 9.4); - Q2 (9.4-10.8); - Q3 (10.9-12.3); - Q4 (>12.3); - PUFA (quintiles; Range, %E); - Q1 (ref; < 3.4); - Q2 (3.4-4.3); - Q3 (4.3-5.4); - Q4 (> 5.4); - Isocaloric replacement (1%E) of SFA and CHO with MUFA, PUFA and CHO (continuous, median intake for each quintile); [underlined: Diet assessment method and timing]:; - 4-d guided food diary followed by a check for completeness by a nutritionist (with the participant).; - Administered at baseline; Outcomes and assessment methods:; - Assessed during mean 21.4y of follow-up; - [underlined: Fatal and non-fatal CHD events] ascertained by record linkage to hospital discharge registries and Finland’s death register.; - [underlined: Fatal CHD events]: 183; - [underlined: Non-fatal CHD events:] 382 | SFA; [underlined: Fatal CHD], HR (95% CI); Q1 (ref) vs Q2,Q3, or Q4: All NS; P-trend=0.68; [underlined: Non-Fatal CHD], HR (95% CI); Q1 (ref) vs Q2,Q3, or Q4: All NS; P-trend=0.66; MUFA; [underlined: Fatal CHD], HR (95% CI); Q1 (ref) vs Q2,Q3, or Q4: All NS; P-trend=0.07; [underlined: Non-Fatal CHD], HR (95% CI); Q1 (ref) vs Q2,Q3, or Q4: All NS; P-trend=0.21; PUFA; [underlined: Fatal CHD], HR (95% CI),; Q1 (ref) vs Q2: 0.67 (0.44–1.03); Q1 (ref) vs Q3: 0.53 (0.31–0.90); Q1 (ref) vs Q4: 0.46 (0.24–0.90); P-trend=0.03; [underlined: Non-Fatal CHD], HR (95% CI); Q1 (ref) vs Q2,Q3, or Q4: All NS; P-trend=0.93; Replacement of SFA (1%E); [underlined: Fatal CHD], HR (95% CI),; With MUFA: Data NR, P<0.05; With PUFA: Data NR, P<0.05; [underlined: Non-Fatal CHD], HR (95% CI),; With MUFA: Data NR, P<0.05; With PUFA: Data NR, P<0.05; Replacement of CHO (1%E); [underlined: Fatal CHD], HR (95% CI),; With SFA: Data NR, P>0.05 (no interaction by low vs high GI CHO); With MUFA: Data NR, P<0.05; With PUFA: Data NR, P<0.05; [underlined: Non-Fatal CHD], HR (95% CI),; With SFA: Data NR, P>0.05 (no interaction by low vs high GI CHO); With MUFA: Data NR, P<0.05; With PUFA: Data NR, P>0.05 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity; Key confounders accounted for: Age, sex, SES (education, income), TEI, smoking, alcohol intake, physical activity, family history of CHD; Additional model adjustments: Examination year, BMI, diabetes, hypertension, intake of fiber, %E protein, %E from remaining fatty acids (MUFA, PUFA, SFA, trans-FA); Limitations:; - Not all key confounders accounted for; - Potential bias in classification of exposures due to use of non-validated FFQ; - No preregistered statistical analysis plan; Funding sources:; University of Eastern Finland.
Virtanen, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/26864369) ^214^; PCS, KIHD (Kuopio Ischaemic Heart Disease Risk Factor Study), Finland; Baseline N=2,682, Analytic N=1,032 (Attrition: 62%); Participant characteristics at baseline:; - Men, aged 42-60 years with no history of stroke or coronary artery disease; - Type 2 diabetes: ~5%; - Age: Mean~52y; - Sex (female): 0%; - Race/ethnicity: NR; - SES: Education: Mean~9y; - Anthropometry: BMI, Mean~26.50; Fat intake at baseline, Mean (SD):; - Cholesterol (mg/d): 398 (147); BP at baseline:; - Hypertension: ~55%; Summary of findings:; Cholesterol intake was not significantly associated with fatal and non-fatal CHD in middle-aged and older men from eastern Finland. | Exposures:; - Cholesterol intake (tertiles, mg/d); - Q1 (ref; < 321); - Q2 (321-438); - Q3 (>438); [underlined: Diet assessment method and timing]:; - 4-d guided food diary followed by a check for completeness by a nutritionist with the participant.; - Administered at baseline; Outcomes and assessment methods:; - Assessed during mean 20.8y, SD=6.5y of follow-up; - [underlined: Fatal and non-fatal CHD events] ascertained by record linkage to hospital discharge registries and Finland’s death register.; - [underlined: CHD events:] 230 | [underlined: Incident CHD], HR (95% CI); Cholesterol intake; Q1 (ref) vs Q2, or Q3: All NS; P-trend=0.96 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity; Key confounders accounted for: Age, sex, SES (education, income), TEI, smoking, alcohol intake, physical activity, family history of CHD; Additional model adjustments: Examination year, BMI, diabetes, hypertension, intake of fruits, berries, and vegetables, fiber, PUFA, and SFA; Limitations:; - Not all key confounders accounted for; - Potential bias in classification of exposures due to use of non-validated FFQ; - No preregistered statistical analysis plan; Funding sources:; University of Eastern Finland.
Koskinen, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/30370878) ^176^; PCS, KIHD (Kuopio Ischemic Heart Disease Risk Factor Study), Finland; Baseline N=2,682, Analytic N=1,981 (Attrition: 26%), Butter analysis N=495; Participant characteristics at baseline:; - Men, aged 42-60 years without CHD; - Type 2 diabetes: ~5%; - Age: Mean~52y; - Sex (female): 0%; - Race/ethnicity: NR; - SES: Education: Mean~9y; - Anthropometry: BMI, Mean~26.5; Fat intake at baseline, Mean (SD):; - Butter intake (g/d): 33 (27); - PUFA (E%): ~4.6; - MUFA (E%): ~11.8; - SFA (E%): ~18; Blood lipids and BP at baseline, Mean:; - LDL (mmol/L): ~4.0; - HDL (mmol/L): ~1.3; - Triglycerides (mmol/L): ~1.26; - Hypertension: ~5%; Summary of findings:; Butter intake was not significantly associated with fatal and non-fatal CHD events in middle-aged and older men from eastern Finland. | Exposures:; - Butter intake (including butter from spreads and recipes) (quartiles, median intake, g/d); - Q1: 4; - Q2: 20; - Q3: 37; - Q4: 63; - Butter intake (continuous, g/d); [underlined: Diet assessment method and timing]:; - 4-d guided food diary followed by a check for completeness by a nutritionist (with the participant); - Administered at baseline; Outcomes and assessment methods:; - Assessed during mean 20.1y, SD=7.2y of follow-up; - [underlined: Fatal and non-fatal CHD events] ascertained by record linkage to hospital discharge registries and Finland’s death register.; - [underlined: CHD events]: 472 CHD cases | [underlined: Incident CHD at 21.1y], HR (95% CI); Butter intake; Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend=0.55; [underlined: Incident CHD at 11y], HR (95% CI); Butter intake (continuous); 0.99 (95% CI 0.57, 1.72; P-trend=0·85) | Key confounders [underlined: NOT] accounted for:; Race/ethnicity; Key confounders accounted for: Age, sex, SES (education, income), TEI, smoking, alcohol intake, physical activity, family history of CVD; Additional model adjustments: Examination year, BMI, use of hypertensive medication, energy adjusted intake of PUFA, intakes of fruits, berries, vegetables, and fiber, presence of diabetes, presence of hypertension; Limitations:; - Not all key confounders accounted for; - Potential bias in classification of exposures due to use of non-validated FFQ; - No preregistered statistical analysis plan; Funding sources:; Finnish Foundation for Cardiovascular Research; Otto A. Malm Foundation; Olvi Foundation; Yrjö Jahnsson Foundation; and North Savo Regional Fund.
Abdollahi, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/31095282) ^135^; PCS, KIHD (Kuopio Ischaemic Heart Disease Risk Factor Study), Finland; Baseline N=2,682, Analytic N=1,950 (Attrition: 27%); Participant characteristics at baseline:; - Men, ages 42-60 y with no history of stroke or coronary artery disease; - Family history of CHD: ~47%; - Family history of stroke: ~20%; - Type 2 diabetes: ~5%; - Age: Mean~52y; - Sex (female): 0%; - Race/ethnicity: NR; - SES: Education: Mean~9y; - Anthropometry: BMI, Mean~26.50; Fat intake at baseline, Mean (SD):; - Cholesterol (mg/d): 408 (150); Blood lipids and BP at baseline, Mean:; - TC (mmol/L): ~5.9; - LDL (mmol/L): ~4.0; - Hypertension: ~55%; Summary of findings:; Cholesterol intake was not significantly associated with stroke risk in middle-aged and older men from eastern Finland. | Exposures:; - Cholesterol intake (continuous, 100mg/d); - Cholesterol intake (quartiles, mg/d); - Q1 (ref; < 333); - Q2 (333-387); - Q3 (388-459); - Q4 (>459); [underlined: Diet assessment method and timing]:; - 4-d guided food diary followed by a check for completeness by a nutritionist (with the participant).; - Administered at baseline; Outcomes and assessment methods:; - Assessed during mean 21.2y, SD=7.2y of follow-up; - Incident stroke events ascertained through FINMONICA (Finnish Monitoring Trends and Determinants in Cardiovascular Diseases) stroke register and by record linkage to hospital discharge registries, Finland’s stroke register and Finland’s death register.; - [underlined: Any stroke]: 217 cases; - [underlined: Ischemic stroke]: 166 cases; - [underlined: Hemorrhagic stroke]: 55 cases | [underlined: Total stroke], HR (95% CI); Cholesterol intake (quartiles); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend=0.42; Cholesterol intake (continuous); 0.98 (95% CI: 0.86, 1.12); [underlined: Ischemic stroke,] HR (95% CI); Cholesterol intake (quartiles); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend=0.32; Cholesterol intake (continuous); 0.97 (95% CI:0.83, 1.13); [underlined: Hemorrhagic stroke,] HR (95% CI); Cholesterol intake (quartiles); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend=0.75; Cholesterol intake (continuous); 0.94 (95% CI: 0.71, 1.23); Similar results were found at the 10y follow-up point. | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Age, sex, SES (education, income), TEI, smoking, alcohol intake, physical activity,; Additional model adjustments: Examination year, BMI, use of hypertensive medication, intake of fruits, berries, and vegetables (g/d); Limitations:; - Not all key confounders accounted for; - Potential bias in classification of exposures due to use of non-validated FFQ; - No preregistered statistical analysis plan; Funding sources:; University of Eastern Finland.
Zhong, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/30874756) ^224^; PCS, LRPP (Lifetime Risk Pooling Project: ARIC, CARDIA, FHS, FOS, FHS, MESA), U.S.; Baseline N=34,497, Analytic N=29,615 (Attrition: 14%); Participant characteristics at baseline:; - No history of CVD; - Use lipid lowering medication: 5.9%; - Use hypertensive medication: 27.5%; - Age: Mean=51.6y; - Sex (female): 55.1%; - Race/ethnicity: 62.1% White, 31.1% Black, 4.4% Hispanic, 2.4% Chinese; - SES: Education: 54.7% Some college or more; - Anthropometry: Mean BMI: 27.6; Fat intake at baseline:; - Cholesterol (mg/d): Median=241, IQR=164-350, Mean=285; Blood lipids and BP at baseline, Mean:; - TC (mg/dL): 203.4; - SBP (mmHg): 121.6; Summary of findings:; Among adults pooled from 6 U.S. prospective cohort studies, with a median follow-up of 17.5 years, higher consumption of dietary cholesterol was significantly associated with higher risk of incident CVD, incident stroke and CVD mortality, but was not associated with incident CHD or heart failure. | Exposures:; - Dietary cholesterol intake, (continuous, per 300mg/d); [underlined: Diet assessment method and timing]:; - Five of 6 cohorts used validated 66 to 158-item FFQs and one cohort (CARDIA) used a validated 700-item diet history.; - Administered at baseline within each cohort; - Standardized protocol used to harmonize data; Outcomes and assessment methods:; - Assessed during median 17.5y of follow-up; - [underlined: Risk of incident CVD] from coronary heart disease, stroke, and heart failure, and other CVD causes ascertained via medical and death records.; - [underlined: Incident CVD events]: 5400 cases; - [underlined: CHD events (fatal and non-fatal):] 2088 cases; - [underlined: Stroke (fatal and non-fatal):] 1302 cases; - [underlined: Heart failure (fatal and non-fatal):] 1897 cases; - [underlined: Other CVD deaths:] 113 cases | Cholesterol; All subjects; [underlined: Incident CVD,] HR (95% CI); Per 300mg/d: 1.14 (1.06, 1.23), P<0.01; [underlined: Incident CHD,] HR (95% CI); Per 300mg/d: 1.12 (1.00, 1.26), P>0.05; [underlined: Incident Stroke,] HR (95% CI); Per 300mg/d: 1.24 (1.07-1.44) P<0.05; [underlined: Incident Heart Failure,] HR (95% CI); Per 300mg/d: 1.11 (0.98-1.27), P>0.05; [underlined: Incident CVD mortality,] HR (95% CI); Per 300mg/d: 1.22 (1.07, 1.40), P<0.05; Subgroup analyses among subjects eating a high -SFA diet (≥138%E) (yes/no) and among subjects eating a low-SFA diet (<7%E) (yes/no) indicated no significant interaction. See Zhong, 2019 for details. | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes; Key confounders accounted for: Age, sex, race/ethnicity, SES, physical activity, TEI, smoking, alcohol intake; Additional model adjustments: Hormone replacement therapy, BMI, diabetes status, SBP, use of antihypertensive medications, (HDL) cholesterol, non-HDL cholesterol, and use of lipid-lowering medications; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; NHLBI; Northwestern University Feinberg School of Medicine.
Sonestedt, 2011 (https://www.ncbi.nlm.nih.gov/pubmed/21660519) ^206^; PCS, MDCC (Malmo Diet and Cancer Cohort, Sweden); Baseline N=28,098, Analytic N=26,445 (Attrition: 6%); Participant characteristics at baseline:; - Men and women without history of MI, stroke, or diabetes at baseline.; - Age: ~57y; - Sex (female): 62%; - Race/ethnicity: NR; - SES: Education, ~41% Elementary, ~27% Primary/Secondary, ~9% Upper secondary, ~9% Further education without degree, ~14% University degree; - Anthropometry: BMI, ~25.2; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline, Mean:; - LDL (mmol/L): ~4.1; - HDL (mmol/L): ~1.3; - Triglycerides (mmol/L): ~1.1; - SBP (mmHg): ~139; - DBP (mmHg): ~85; Summary of findings:; In men and women, butter intake at ~57y of age was not significantly associated with incident CVD during ~12y of follow-up. | Exposures:; - Butter (non-consumers and tertiles of consumers; energy adjusted g/d); - C1 (ref): No intake; - C2: Men, Mean=8; Women, Mean=5; - C3: Men, Mean=31; Women, Mean=18; - C4: Men, Mean=61; Women, Mean=41; [underlined: Assessment method and timing]:; - Validated 168-item FFQ assessing intake over past year and seven-d menu book; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~12y of follow-up; - [underlined: Incident CVD:] Obtained via linkage with Swedish Hospital Discharge Register, Cause-of-death Register, and STROMA (local stroke register in Malmo); - [underlined: Total:] 2520 cases; - [underlined: Coronary event (fatal or non-fatal MI or death due to IHD):] 1344 cases; - [underlined: Stroke:] 1176 cases | [underlined: Incident CVD (total),] HR (95% CI); C1 (ref) vs C2, C3, or C4: All NS; P-trend=0.16; [underlined: Incident Coronary Event,] HR (95% CI); C1 (ref) vs C2, C3, or C4: All NS; P-trend=0.24; [underlined: Incident Stroke,] HR (95% CI); C1 (ref) vs C2, C3, or C4: All NS; P-trend=0.60 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: Diet assessment method, season of data collection; Incident CVD (total): intake of vegetables, fruit and berries, fish and shellfish, meat, coffee, and whole grains.; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of participants with diabetes at baseline; - Analyses did not account for co-exposures (other types of FA); - No preregistered statistical analysis plan; Funding sources:; Lund University Diabetes Center; Swedish Medical Research Council; Swedish Heart and Lung Foundation; Region Skane; Skane University Hospital Foundation; Albert Pahlsson Research Foundation; Crafoord Foundation
Wallstrom, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22384046) ^217^; PCS, MDCC (Malmo Diet and Cancer Cohort), Sweden; Baseline N=28,098, Analytic N=20,674 (Attrition: 26%); Participant characteristics at baseline:; - Men and women without history of MI, stroke, or diabetes at baseline.; - Age: Mean~58y; - Sex (female): 61%; - Race/ethnicity: NR; - SES: Education, ~42% ≤7y, ~26% 8-9y, ~9% 10-12y, ~23% >12y; - Anthropometry: BMI, ~1% <18.5, ~48% 18.5-24.99, ~39% 25.0-29.99, ~12% ≥30; Fat intake at baseline:; - See “Exposures” in next column; BP at baseline, Mean:; - SBP (mmHg): ~141; - DBP (mmHg): ~86; Summary of findings:; In men and women, consumption of MUFA, total PUFA, n-3 PUFA, long-chain n-3 PUFA, and n-6 PUFA at ~58y of age was not associated with incident ischemic CVD (total, coronary event, or stroke) during ~13.5y of follow-up. Higher SFA intake in women was significantly associated with lower risk of coronary events; however, no significant association was detected for total ischemic CVD or stroke in women or any ischemic CVD outcome in men. | Exposures (medians):; - SFA (quintiles; %E); - Q1 (Men, 13; Women, 12.9), Q2 (Men, 15.2; Women, 15.1), Q3 (Men, 16.8; Women, 16.7), Q4 (Men, 18.9; Women, 18.6), Q5 (Men, 22.7; Women, 22.1); - MUFA (quintiles; %E); - Q1 (Men, 13.0; Women, 11.0), Q2 (Men, 11.4; Women, 12.5), Q3 (Men, 13.1; Women, 13.6), Q4 (Men, 14.2; Women, 14.6), Q5 (Men, 15.3; Women, 16.1); [underlined: Assessment method and timing]:; - Validated 168-item FFQ assessing intake over past year and seven-d menu book; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~13.5y of follow-up; - [underlined: Incident Total Ischemic CVD:] Obtained via linkage with National Patient Register, National Cause of Death Register, and Stroke Register in Malmo; Included MI (fatal and nonfatal), death from chronic ischemic heart disease, cerebral infarction, or non-specific stroke; - [underlined: Total:] 1089 cases in men, 687 cases in women; - [underlined: Coronary event (MI or death from chronic ischemic heart disease):] 688 cases in men, 333 cases in women; - [underlined: Ischemic stroke:] 401 cases in men, 354 cases in women; Exposures (medians):; - PUFA (quintiles; %E); - Q1 (Men, 4.5; Women, 4.3), Q2 (Men, 5.5; Women, 5.1), Q3 (Men, 6.2; Women, 5.8), Q4 (Men, 7.1; Women, 6.6), Q5: Men, 8.5; Women, 8.0); - n-6 PUFA (quintiles; %E); - Q1 (Men, 3.5; Women, 3.3), Q2 (Men, 4.3; Women, 4.0), Q3 (Men, 5.0; Women, 4.7), Q4 (Men, 5.8; Women, 5.4), Q5 (Men, 7.1; Women, 6.7); Exposures (medians):; - n-3 PUFA (quintiles; %E); - Q1 (Men, 0.70; Women, 0.67), Q2 (Men, 0.86; Women, 0.82), Q3 (Men, 0.99; Women, 0.94), Q4 (Men, 1.14; Women, 1.08), Q5 (Men, 1.40; Women, 1.34); - Long chain n-3 PUFA (quintiles; %E); - Q1 (Men, 0.08; Women, 0.07), Q2 (Men, 0.13; Women, 0.12), Q3 (Men, 0.19; Women, 0.18), Q4 (Men, 0.30; Women, 0.27), Q5 (Men, 0.53; Women, 0.49) | SFA; [underlined: Incident Ischemic CVD (total),] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.32; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.22; [underlined: Incident Coronary Event,] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.12; Women:; Q1 (ref) vs Q2: 0.68 (0.48, 0.95); Q1 (ref) vs Q3: 0.68 (0.48, 0.96); Q1 (ref) vs Q4: 0.60 (0.41, 0.86); Q1 (ref) vs Q5: 0.67 (0.46, 0.97); P-trend=0.037; [underlined: Incident Ischemic Stroke,] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.69; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.75; MUFA; [underlined: Incident Ischemic CVD (total),] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.64; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.94; [underlined: Incident Coronary Event,] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.27; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.99; [underlined: Incident Ischemic Stroke,] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.47; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.90; PUFA; [underlined: Incident Ischemic CVD (total),] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.98; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.91; [underlined: Incident Coronary Event,] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.88; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.32; [underlined: Incident Ischemic Stroke,] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.82; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.42; n-6 PUFA; [underlined: Incident Ischemic CVD (total),] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.62; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.75; [underlined: Incident Coronary Event,] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.96; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.55; [underlined: Incident Ischemic Stroke,] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.46; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.32; n-3 PUFA; [underlined: Incident Ischemic CVD (total),] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.92; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.50; [underlined: Incident Coronary Event,] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.82; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.14; [underlined: Incident Ischemic Stroke,] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.91; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.63; Long chain n-3 PUFA; [underlined: Incident Ischemic CVD (total),] HR (95% CI); Men:; Q1 (ref) vs Q2: 1.24 (1.02, 1.51); Q1 (ref) vs Q3: 1.22 (1.00, 1.48); Q1 (ref) vs Q4: 1.09 (0.89, 1.33); Q1 (ref) vs Q5: 1.03 (0.84, 1.26); P-trend=0.59; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.25; [underlined: Incident Coronary Event,] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.57; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.31; [underlined: Incident Ischemic Stroke,] HR (95% CI); Men: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.89; Women: Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.53 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: Diet assessment method, season of data collection, BMI, SBP, antihypertensive treatment, antihyperlipidemic treatment, energy adjusted dietary fiber; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of participants with diabetes at baseline; - Analyses did not account for co-exposures (other types of FA); - No preregistered statistical analysis plan; Funding sources:; Swedish governmental funds for clinical research (ALF); Heart-Lung Foundation; Region Skane; Research funds of Skane University Hospital; Ernhold Lundstrom Foundation
Hlebowicz, 2013 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3733649/) ^167^; PCS, MDCC (Malmo Diet and Cancer Cohort), Sweden; Baseline N=28,098 Analytic N=17,126 (Attrition: 39%); Participant characteristics at baseline:; - Men and women without history of MI, stroke, or diabetes at baseline.; - Age: ~58y; - Sex (female): 59%; - Race/ethnicity: NR; - SES: Education, ~40% <9y, ~27% 9y, ~18% High school degree, ~15% University/college degree; - Anthropometry: WC, Men~93cm, Women~77cm; Fat intake at baseline:; - See “Exposures” in next column; BP at baseline:; - SBP (mmHg): ~140; - DBP (mmHg): ~85; Summary of findings:; In men and women, adherence to SFA or PUFA intake recommendations at ~58y of age was not associated with risk of incident CVD events through 16y of follow-up. | Exposures:; - SFA (dichotomized; adherence to recommended intake of ≤14%E); - Non-adherence (ref; n~5719 men, n~8434 women): ≥14%E; - Adherence (n~1221 men, n~1752): ≤14%E; - PUFA (dichotomized; adherence to recommended intake of 5-10%E); - Non-adherence (ref; n~1464 men, n~2842 women): <5%E or >10%E; - Adherence (n~5476 men, n~7344): 5-10%E; [underlined: Assessment method and timing]:; - Validated 168-item FFQ assessing intake over past year and seven-d menu book; - Assessed at baseline; Outcomes and assessment methods:; - Assessed up to 16y of follow-up; - [underlined: Incident CVD:] Obtained via linkage with Swedish Hospital Discharge Register, National Myocardial Infarction Register, Stroke Register of Malmo (STROMA), and National Cause of Death Register; Included fatal and nonfatal MI, fatal and nonfatal ischemic or non-specific stroke, death attributable to ischemic heart disease.; - [underlined: Total events:] 1797 cases (1093 in men, 703 in women) | SFA; [underlined: Incident CVD,] HR (95% CI); Men:; Non-adherence (ref) vs Adherence: NS; Women:; Non-adherence (ref) vs Adherence: NS; PUFA; [underlined: Incident CVD,] HR (95% CI); Men:; Non-adherence (ref) vs Adherence: NS; Women:; Non-adherence (ref) vs Adherence: NS | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: Diet assessment method, season of data collection, WC, PUFA or SFA (as applicable), fish and shellfish, dietary fiber, fruit and vegetables, sucrose.; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of participants with diabetes at baseline; - Analyses did not account for co-exposures (other types of FA); - No preregistered statistical analysis plan; Funding sources:; Swedish Heart-Lung Foundation; Swedish Research Council; Swedish Government funds for clinical research (ALF); Foundations for Research at Skane University Hospital Malmo; Ernhold Lundstrom’s Foundation; Funds by Region Skane
Hellstrand, 2014 (https://www.ncbi.nlm.nih.gov/pubmed/25008580) ^165^; PCS, MDCC (Malmo Diet and Cancer Cohort), Sweden; Baseline N=28,098 Analytic N=24,032 (Attrition: 14%); Participant characteristics at baseline:; - Men and women without history of MI, stroke, or diabetes at baseline.; - Age: ~58y; - Sex (female): 62%; - Race/ethnicity: NR; - SES: Education, ~41% Elementary, ~27% Primary and secondary, ~9% Upper secondary, ~9% Additional education without a degree, ~14% University degree; - Anthropometry: BMI, Mean~25.7; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - NR; Summary of findings:; In men and women, n-3 and n-6 PUFA intake at ~58y of age was not associated with risk of incident CVD events during ~14y of follow-up except for some comparisons between intake quintiles for total n-6 PUFA and LA. However, the test of trend was non-significant. | Exposures (medians):; - Total n-3 PUFA (continuous & quintiles; %E); - Q1 (0.68), Q2 (0.83), Q3 (0.96), Q4 (1.10), Q5 (1.37); - ALA (quintiles; %E); - Q1 (0.52), Q2 (0.63), Q3 (0.72), Q4 (0.82), Q5 (0.99); - Long-chain n-3 PUFA [EPA, DHA, DPA] (quintiles; %E); - Q1 (0.07), Q2 (0.13), Q3 (0.19), Q4 (0.30), Q5 (0.53); - Total n-6 PUFA (quintiles; %E); - Q1 (3.32), Q2 (4.11), Q3 (4.79), Q4 (5.55), Q5 (6.86); - LA (quintiles; %E); - Q1 (3.26), Q2 (4.05), Q3 (4.73), Q4 (5.49), Q5 (6.80); - ALA:LA Ratio (quintiles); - Q1 (0.12), Q2 (0.14), Q3 (0.15), Q4 (0.17), Q5 (0.21); - n-3:n-6 PUFA Ratio (quintiles); - Q1 (0.14), Q2 (0.17), Q3 (0.19), Q4 (0.23), Q5 (0.30); [underlined: Assessment method and timing]:; - Validated 168-item FFQ assessing intake over past year and seven-d menu book; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~14y of follow-up; - [underlined: Incident CVD:] Obtained via linkage with Swedish Hospital Discharge Register, National Cause-of-Death Register, and local stroke register in Malmo (STROMA); Included coronary events (fatal/nonfatal MI, death due to ischemic heart disease) and ischemic stroke; - [underlined: Total:] 2648 cases (1539 men, 1109 women) | Total n-3 PUFA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; Per 1%E: P=NS; ALA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; Per 1%E: P=NS; Long-chain n-3 PUFA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; Per 1%E: P=NS; Total n-6 PUFA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2: 1.15 (1.02, 1.30); Q1 (ref) vs Q3: 1.09 (0.96, 1.23); Q1 (ref) vs Q4: 0.99 (0.87, 1.12); Q1 (ref) vs Q5: 1.16 (1.03, 1.31); Per 1%E: 1.01 (0.99, 1.04); LA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2: 1.15 (1.02, 1.30); Q1 (ref) vs Q3: 1.08 (0.96, 1.22); Q1 (ref) vs Q4: 0.99 (0.88, 1.13); Q1 (ref) vs Q5: 1.16 (1.02, 1.30); Per 1%E: 1.01 (0.99, 1.04); ALA:LA Ratio; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; Per 1%E: P=NS; n-3:n-6 PUFA Ratio; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; Per 1%E: P=NS | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: Diet assessment method, season of data collection, BMI.; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of participants with diabetes at baseline; - FFQ had low validity for long-chain n-3 PUFAs; - Analyses did not account for co-exposures (other types of FA); - No preregistered statistical analysis plan; Funding sources:; Swedish Heart-Lung Foundation; Swedish Research Council; Swedish Government funds for clinical research (ALF); Foundations for Research at Skane University Hospital Malmo; Ernhold Lundstrom’s Foundation; Funds by Region Skane
Kulezic, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/31431146) ^178^; PCS, MDCC (Malmo Diet and Cancer Cohort), Sweden; Baseline N=28,098 Analytic N=26,010 (Attrition: 7%); Participant characteristics at baseline:; - Men and women without history of PAD, CVD, abdominal aortic aneurysm, or diabetes at baseline.; - Age: ~58y; - Sex (female): 62%; - Race/ethnicity: NR; - SES: Education, ~41% <9y, ~26% Elementary school, ~9% Upper secondary, ~9% University without a degree, ~15% University degree; - Anthropometry: BMI, Mean~25.6; Fat intake at baseline, Mean:; - SFA: ~16%E; - PUFA: ~6%E; Blood lipids and BP at baseline:; - Hypertension: ~76%; Summary of findings:; In men and women, adherence to SFA or PUFA intake recommendations at ~58y of age was not associated with risk of incident peripheral artery disease. | Exposures:; - SFA (dichotomized; adherence to recommended intake of ≤14%E); - Non-adherence (ref; 18,559): ≥14%E; - Adherence (n=7,451): ≤14%E; - PUFA (dichotomized; adherence to recommended intake of 5-10%E); - Non-adherence (ref; n=8,160): <5%E or >10%E; - Adherence (n=17,850): 5-10%E; [underlined: Assessment method and timing]:; - Validated 168-item FFQ assessing intake over past year and seven-d menu book; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~21.7y of follow-up; - [underlined: Incident PAD:] Obtained via linkage with Cause of Death Register and Inpatient and Outpatient Registers; Included first diagnosis or surgical procedures for peripheral artery disease (PAD); - [underlined: Total:] 1122 cases | SFA; [underlined: Incident PAD,] HR (95% CI); Non-adherence (ref) vs Adherence: NS; PUFA; [underlined: Incident PAD,] HR (95% CI); Non-adherence (ref) vs Adherence: NS | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes.; Key confounders accounted for: Sex, age, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: Diet assessment method, season of data collection, SFA or PUFA (as applicable), fish and shellfish, fiber, fruit and vegetables, sucrose.; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of participants with diabetes at baseline; - No preregistered statistical analysis plan; Funding sources:; NR
de Oliveira Otto, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22760560) ^156^; PCS, MESA (Multi-Ethnic Study of Atherosclerosis), U.S.; Baseline N=6,814 Analytic N=5,209 (Attrition: 24%); Participant characteristics at baseline:; - Men and women 45-84y of age without CVD or type 2 diabetes at baseline; - Age: ~62y; - Sex (female): ~52%; - Race/ethnicity: ~44% White, ~24% African American, ~20% Hispanic, ~12% Chinese; - SES: ~84% ≥12y of formal education; - Anthropometry: BMI, ~27.9; Fat intake at baseline:; - Total SFA (g/d): ~18.4; - Dairy SFA (g/d): ~6.2; - Meat SFA (g/d): ~3.0; - Butter SFA (g/d): ~0.7; - Plant SFA (g/d): ~0.9; - Mixed sources SFA (g/d): ~4.5; Blood lipids and BP at baseline, Mean:; - LDL (mg/dL): ~118; - HDL (mg/dL): ~52; - SBP (mmHg): ~126; - DBP (mmHg): ~72; Summary of findings:; In men and women, higher intake of total SFA and dairy SFA at ~62y of age was significantly associated with lower risk of incident total CVD and CHD over 10y of follow-up. Higher intake of meat SFA was significantly associated was higher risk of total CVD and CHD. Replacement of meat SFA with dairy SFA was significantly associated with lower risk of total CVD and CHD. Intake of butter, plant, and mixed sources of SFA was not significantly associated with total CVD and CHD. | Exposures:; - Total SFA (continuous; per 5g/d or per 5%E); - Dairy SFA (continuous; per 5g/d or per 5%E); - Meat SFA (continuous; per 5g/d or per 5%E); - Butter SFA (continuous; per 5g/d or per 5%E); - Plant SFA (continuous; per 5g/d or per 5%E); [underlined: Assessment method and timing]:; - Modified, Block 120-item FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed through 10y of follow-up; - [underlined: Incident CVD:] Obtained through cohort examinations, follow-up calls, medical record abstractions, or obituaries (reviewed by medical endpoints committee); CVD included CHD events (MI, cardiac arrest, definite/probable angina, CHD death), stroke, stroke death, or other CVD/atherosclerotic death; - [underlined: Total CVD:] 316 cases; - [underlined: CHD events:] 231 cases; Exposures:; - Mixed sources of SFA (continuous; per 5g/d or per 5%E); - Replacement of SFA from different sources (continuous; per 2%E); - Replacing Meat SFA with Dairy, Butter, or Plant SFA; - Replacing Dairy SFA with Butter or Plant SFA; - Replacing Butter SFA with Plant SFA | Total SFA; [underlined: Incident CVD,] HR (95% CI); Per 5g/d: 0.86 (0.75, 0.97), P=0.02; Per 5%E: 0.71 (0.56, 0.89), P<0.01; [underlined: Incident CHD Events,] HR (95% CI); Per 5g/d: 0.86 (0.74, 1.00), P=0.05; Per 5%E: 0.73 (0.56, 0.96), P=0.02; Dairy SFA; [underlined: Incident CVD,] HR (95% CI); Per 5g/d: 0.79 (0.68, 0.92), P<0.01; Per 5%E: 0.62 (0.47, 0.82), P<0.01; [underlined: Incident CHD Events,] HR (95% CI); Per 5g/d: 0.84 (0.71, 0.99), P=0.03; Per 5%E: 0.71 (0.52, 0.98), P=0.03; Meat SFA; [underlined: Incident CVD,] HR (95% CI); Per 5g/d: 1.26 (1.02, 1.54), P=0.03; Per 5%E: 1.48 (0.98, 2.23), P=0.06; [underlined: Incident CHD Events,] HR (95% CI); Per 5g/d: 1.29 (1.03, 1.62), P=0.03; Per 5%E: 1.57 (0.98, 2.51), P=0.06; Processed meat SFA: Both NS; Unprocessed meat SFA:; Per 5g/d: 1.51 (1.12, 2.05), P<0.01; Per 5%E: 2.22 (1.20, 4.08), P=0.01; Butter SFA; [underlined: Incident CVD,] HR (95% CI); Per 5g/d: 0.87 (0.66, 1.15), P=0.33; Per 5%E: 0.83 (0.50, 1.37), P=0.47; [underlined: Incident CHD Events,] HR (95% CI); Per 5g/d: 0.79 (0.55, 1.12), P=0.18; Per 5%E: 0.67 (0.35, 1.27), P=0.20; Plant SFA; [underlined: Incident CVD,] HR (95% CI); Per 5g/d: 1.00 (0.50, 2.01), P=0.99; Per 5%E: 0.62 (0.18, 2.11), P=0.44; [underlined: Incident CHD Events,] HR (95% CI); Per 5g/d: 1.00 (0.44, 2.25), P=0.99; Per 5%E: 2.09 (0.19, 23.04), P=0.63; Mixed source of SFA; [underlined: Incident CVD,] HR (95% CI); Per 5g/d: 1.01 (0.77, 1.32), P=0.96; Per 5%E: 0.83 (0.51, 1.36), P=0.51; [underlined: Incident CHD Events,] HR (95% CI); Per 5g/d: 0.90 (0.65, 1.24), P=0.47; Per 5%E: 0.68 (0.38, 1.24), P=0.19; Replacement of Meat SFA (per 2%E); [underlined: Incident CVD,] HR (95% CI); With Dairy SFA: 0.75 (0.63, 0.91); With Butter SFA: 0.81 (0.64, 1.03); With Plant SFA: 0.63 (0.38, 1.03); [underlined: Incident CHD Events,] HR (95% CI); With Dairy SFA: 0.76 (0.61, 0.94); With Butter SFA: 0.71 (0.53, 0.95); With Plant SFA: 0.62 (0.35, 1.11); Replacement of Dairy SFA (per 2%E); [underlined: Incident CVD,] HR (95% CI); With Butter SFA: 1.08 (0.88, 1.33); With Plant SFA: 0.83 (0.52, 1.33); [underlined: Incident CHD Events,] HR (95% CI); With Butter SFA: 0.94 (0.72, 1.22); With Plant SFA: 0.82 (0.48, 1.42); Replacement of Butter SFA (per 2%E); [underlined: Incident CVD,] HR (95% CI); With Plant SFA: 0.77 (0.48, 1.25); [underlined: Incident CHD Events,] HR (95% CI); With Plant SFA: 0.88 (0.50, 1.55) | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: Study center, BMI, dietary supplement use, use of cholesterol-lowering medication, fruit and vegetable intake, energy adjusted intake of dietary fiber, vitamin E, trans fat, and PUFA; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of participants with diabetes at baseline; - No preregistered statistical analysis plan; Funding sources:; University of Texas Health Innovation for Cancer Prevention Research Postdoctoral Fellowship; University of Texas School of Public Health – Cancer Prevention and Research Institute of Texas; NIDDK; NHLBI.
de Oliveira Otto, 2013 (https://www.ncbi.nlm.nih.gov/pubmed/24351702) ^157^; PCS, MESA (Multi-Ethnic Study of Atherosclerosis), U.S.; Baseline N=2,880 (random subset of total 6,814 participants) Analytic N=2,372 (Attrition: 18%); Participant characteristics at baseline:; - Men and women 45-84y of age without CVD at baseline; - Age: Mean=61.5y, SD=10.2y; - Sex (female): 53.2%; - Race/ethnicity: ~25% White, ~25% African American, ~25% Hispanic, ~25% Chinese; - SES: 60.3% with some college degree; - Anthropometry: BMI, Mean=27.9, SD=5.5; Fat intake at baseline:; - ALA (g/d): 1.0 (0.6); - LA (g/d): 9.0 (6.3); - AA (g/d): 0.12 (0.08); - EPA (mg/d): 45 (50); - DPA (mg/d): 20 (20); - DHA (mg/d): 82 (73); Blood lipids and BP at baseline: NR; Summary of findings:; In men and women, higher intakes of EPA, DPA, and DHA at ~62y of age were significantly associated with lower risk of total incident CVD and CHD through 10y of follow-up. When modeled continuously, intake of ALA, LA, and AA were not significantly associated with total incident CVD and CHD. However, those in the 2^nd^ quartile of intake for LA and AA+LA had a significantly lower risk of incident CVD and CHD compared to the 1^st^ quartile of intake. | Exposures:; - EPA (continuous; per 1-IQR unit [80mg/d]); - EPA (quartiles; mg/d), Medians (Q1 (10), Q2 (20), Q3 (40), Q4 (90)); - DPA (continuous; per 1-IQR unit [35mg/d]); - DPA (quartiles; mg/d), Medians (Q1 (4), Q2 (10), Q3 (19), Q4 (39)); - DHA (continuous; per 1-IQR unit [130mg/d]); - DHA (quartiles; mg/d), Medians (Q1 (20), Q2 (50), Q3 (80), Q4 (150)); - EPA+DPA+DHA (continuous; per 1-IQR unit [240mg/d]); - EPA+DPA+DHA (quartiles; mg/d), Medians (Q1 (40), Q2 (80), Q3 (140), Q4 (280)); - ALA (continuous; per 1-IQR unit [1200mg/d]); - ALA (quartiles; mg/d), Medians (Q1 (390), Q2 (690), Q3 (1020), Q4 (1610)); - LA (continuous; per 1-IQR unit [11100mg/d]); - LA (quartiles; mg/d), Medians (Q1 (3870), Q2 (6230), Q3 (9220), Q4 (14980)); - AA (continuous; per 1-IQR unit [160mg/d]); - AA (quartiles; mg/d), Medians (Q1 (40), Q2 (80), Q3 (120), Q4 (200)); - LA+AA (continuous; per 1-IQR unit [11200mg/d]); - LA+AA (quartiles; mg/d), Medians (Q1 (4000), Q2 (6300), Q3 (9400), Q4 (15200)); Outcomes and assessment methods:; - Assessed through 10y of follow-up; - [underlined: Incident CVD:] Obtained through cohort examinations, follow-up calls, medical record abstractions, or obituaries (reviewed by medical endpoints committee); CVD included CHD events (MI, cardiac arrest, definite/probable angina, CHD death), stroke, stroke death, or other CVD/atherosclerotic death; - [underlined: Total CVD:] 189 cases; - [underlined: CHD events:] 161 cases | EPA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2: 0.94 (0.62, 1.42); Q1 (ref) vs Q3: 0.65 (0.42, 1.03); Q1 (ref) vs Q4: 0.60 (0.37, 0.98); P-trend: 0.03; Continuous: 0.67 (0.46, 0.97); [underlined: Incident CHD Events,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend: 0.06; Continuous: P=NS; DPA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2: 1.10 (0.74, 1.63); Q1 (ref) vs Q3: 0.67 (0.42, 1.07); Q1 (ref) vs Q4: 0.59 (0.35, 0.97); P-trend: 0.02; Continuous: 0.70 (0.48, 1.02); [underlined: Incident CHD Events,] HR (95% CI); Q1 (ref) vs Q2: 1.19 (0.76, 1.86); Q1 (ref) vs Q3: 0.74 (0.50, 1.26); Q1 (ref) vs Q4: 0.54 (0.29, 0.99); P-trend: 0.02; Continuous: 0.65 (0.41, 1.03); DHA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2: 0.98 (0.64, 1.49); Q1 (ref) vs Q3: 0.92 (0.59, 1.44); Q1 (ref) vs Q4: 0.60 (0.35, 1.02); P-trend: 0.048: Continuous: 0.66 (0.44, 1.00); [underlined: Incident CHD Events,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend: 0.09; Continuous: P=NS; EPA+DPA+DHA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2: 1.16 (0.77, 1.75); Q1 (ref) vs Q3: 0.81 (0.52, 1.28); Q1 (ref) vs Q4: 0.64 (0.38, 1.09); P-trend: 0.05; Continuous: 0.66 (0.44, 0.98); [underlined: Incident CHD Events,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend: 0.08; Continuous: NR; ALA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend: 0.20; Continuous: P=NS; [underlined: Incident CHD Events,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend: 0.24; Continuous: P=NS; LA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2: 0.47 (0.28, 0.78); Q1 (ref) vs Q3: 0.87 (0.54, 1.41); Q1 (ref) vs Q4: 0.74 (0.38, 1.43); P-trend: 0.81; Continuous: 0.83 (0.55, 1.25); [underlined: Incident CHD Events,] HR (95% CI); Q1 (ref) vs Q2: 0.45 (0.25, 0.80); Q1 (ref) vs Q3: 0.79 (0.45, 1.37); Q1 (ref) vs Q4: 0.71 (0.33, 1.51); P-trend: 0.73; Continuous: 1.20 (0.60, 2.40); AA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend: 0.34; Continuous: P=NS; [underlined: Incident CHD Events,] HR (95% CI); Q1 (ref) vs Q2, Q3, Q4: All NS; P-trend: 0.45: Continuous: P=NS; AA+LA; [underlined: Incident CVD,] HR (95% CI); Q1 (ref) vs Q2: 0.49 (0.30, 0.81); Q1 (ref) vs Q3: 0.87 (0.54, 1.41); Q1 (ref) vs Q4: 0.74 (0.38, 1.44); P-trend: 0.77: Continuous: 1.14 (0.63, 2.05); [underlined: Incident CHD Events,] HR (95% CI); Q1 (ref) vs Q2: 0.48 (0.27, 0.85); Q1 (ref) vs Q3: 0.79 (0.45, 1.38); Q1 (ref) vs Q4: 0.72 (0.33, 1.53); P-trend: 0.71: Continuous: 1.20 (0.60, 2.41) | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: Study center, BMI, prevalent diabetes, weekly dietary supplement use, hypertensive medication use, fruits and vegetables, processed and unprocessed meat, fiber, vitamin E, SFA, trans-fat; Limitations:; - Not all key confounders accounted for; - Analyses did not account for co-exposures (other types of FA); - No preregistered statistical analysis plan; Funding sources:; Harvard-Bunge Fellowship Program in Nutrition and Health; NHLBI
Ricci, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/29498349) ^201^; PCS, NHANES (National Health and Nutrition Examination Survey), U.S.; Baseline N=40,870 Analytic N=18,372 (Attrition: 55%); Participant characteristics at baseline:; - No CVD, diabetes and cancer; - Age: Median=60.2y; - Sex (female): 48.2%; - Race/ethnicity: 21% Black, 53.8% white, 25% other; - SES: 14% University degree; - Anthropometry: BMI, Median=27; Fat intake at baseline, Median:; - SFAs (%E): 10.8; - PUFAs (%E): 6.3; - MUFA (%E): 12.1; - Cholesterol (mg/1000kcal): Men 183.6±53.2, Women: 200.6±59.0; Blood lipids and BP at baseline, Mean:; - SBP (mmHg): 130.1; - DBP (mmHg): 71.3; Summary of findings:; In U.S. adults, higher saturated fat consumption was associated with increased risk of CVD mortality; high intake of polyunsaturated fat was associated with reduced CVD mortality risk; and there was no association between monounsaturated intake and CVD mortality during approximately 6 year follow-up. Substitution of saturated fat intake with polyunsaturated fat led to beneficial CVD mortality reduction during 6-year follow-up. | Exposures:; - SFA intake (tertiles, %E), Median Q1-Q3; - Q1-Q3: 8·3, 12·4; - T1: 7.1%; - T2: 10.5%; - T3: 14.5%; - MUFA intake (tertiles, %E),; - T1: 8.4%; - T2: 12.0%; - T3: 15.9%; - PUFA intake (tertiles, %E),; - T1: 4.4%; - T2: 6.7%; - T3: 10.2%; - Iso-caloric substitution of SFA with MUFA and PUFA (continuous, per 10%E); [underlined: Diet assessment method and timing]:; - NHANES 1990 – 2002: 24-h dietary recall and dietary post interview; - NHANES 2001 −2010: 2d recall and post recall; - Post recall: 3-10 d from the first dietary evaluation; - Administered at baseline by trained staff; Outcomes and assessment methods:; - Assessed during mean 6.1y of follow-up; - [underlined: CVD mortality] risk assessed via link to U.S. death registry; - CVD mortality: 267 | [underlined: CVD deaths,] HR (95% CI); SFA (tertiles); T1 (ref) vs T2: 1.08 (1.03, 1.12); T1 (ref) vs T3: 1.12 (1.06, 1.17); P for trend< 0.0002; MUFA (tertiles); T1 (ref), T2 or T3: All NS; P-trend=0.37; PUFA (tertiles); T1 (ref) vs T2: 1.01 (0.97, 1.05); T1 (ref) vs T3: 0.93 (0.89, 0.97); P for trend< 0.002; Replacement of 10% SFA, HR (95% CI); MUFA: 0.97 (0.93, 1.01), P<0.0621; PUFA: 0.92 (0.90, 0.95), P<0.05; Replacement of 10% MUFA, HR (95% CI); SFA: 1.03 (0.99, 1.07), NS; PUFA: 0.95 (0.91, 0.99), P<0.05; Replacement of 10% PUFA, HR (95% CI); SFA: 1.08 (1.06, 1.11), P<0.05; MUFA: 1.05 (1.10, 1.10), P<0.05) | Key confounders [underlined: NOT] accounted for:; Age, sex, TEI, family history of CVD or diabetes; Key confounders accounted for: SES (education), ethnicity, alcohol intake, smoking, physical activity; Additional model adjustments: BMI, BP, fiber intake; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to excluding participants with diabetes; - Unlikely that analyses removed risk of bias due to missing data; - No preregistered statistical analysis plan; Funding sources:; No funding received
Zhuang, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/29551407) ^225^; PCS, NHANES (National Health and Nutrition Examination Survey), U.S.; Baseline N=45,082 Analytic N=36,032 (Attrition: 20%); Participant characteristics at baseline:; - Men and women ≥20y of age without CVD or cancer at baseline.; - Age: ~44y; - Sex (female): ~51%; - Race/ethnicity: ~43% non-Hispanic Caucasian, ~24% non-Hispanic Black, ~25% Hispanic, ~8% other; - SES: Greater than high school education ~40%; - Anthropometry: BMI, ~27; Fat intake at baseline:; - See “Exposures” in next column; BP at baseline:; - History of Hypertension: ~36%; Summary of findings:; In men and women, higher marine long chain n-3 PUFA intake at ~44y of age was significantly associated with lower risk of total vascular mortality, heart disease mortality, and stroke mortality during ~9.1y of follow-up. Higher AA intake was significantly associated with lower total vascular mortality and heart disease mortality. Total n-3 PUFA, ALA (except at the highest quartile of intake), total n-6 PUFA, and LA intake, as well as the n-6:n-3 PUFA intake ratio was not significantly associated with vascular mortality. | - Total n-3 PUFA (quartiles; g/d); - Q1: 0-0.78, Q2: 0.78-1.25, Q3: 1.25-1.97, Q4: ≥1.97; - Marine long chain n-3 PUFA (quartiles; mg/d); - Q1: 0, Q2: 0-33.0, Q3: 33.0-100.0, Q4: ≥100.0; - ALA (quartiles; g/d); - Q1: 0-0.70, Q2: 0.70-1.15, Q3: 1.15-1.80, Q4: ≥1.80; - Total n-6 PUFA (quartiles; g/d); - Q1: 0-7.55, Q2: 7.55-12.50, Q3: 12.50-19.34, Q4: ≥19.34; - LA (quartiles; g/d); - Q1: 0-7.43, Q2: 7.43-12.32, Q3: 12.32-19.17, Q4: ≥19.17; - AA (quartiles; mg/d); - Q1: 0-55.0, Q2: 55.0-100.0, Q3: 100.0-200.0, Q4: ≥200.0; - n-6:n-3 PUFA ratio (quartiles); - Q1: ≤8, Q2: 8-10, Q3: 10-12, Q4: ≥12; [underlined: Assessment method and timing]:; - One, 24-hr dietary recall administered by trained interviewers; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~9.1y of follow-up; - [underlined: Vascular Mortality:] Measured via probabilistic record linkage with National Death Index; - [underlined: Total Vascular Mortality:] 1,299 cases; - [underlined: Heart Disease Mortality:] 978 cases; - [underlined: Stroke Mortality:] 321 cases | Total n-3 PUFA; [underlined: Vascular Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.32; [underlined: Heart Disease Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.42; [underlined: Stroke Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.61; Marine long chain n-3 PUFA; [underlined: Vascular Mortality,] HR (95% CI); Q1 (ref) vs Q2: 0.55 (0.41, 0.75); Q1 (ref) vs Q3: 0.65 (0.53, 0.81); Q1 (ref) vs Q4: 0.77 (0.61, 0.98); P-trend: 0.002; [underlined: Heart Disease Mortality,] HR (95% CI); Q1 (ref) vs Q2: 0.56 (0.41, 0.78); Q1 (ref) vs Q3: 0.66 (0.52, 0.84); Q1 (ref) vs Q4: 0.73 (0.53, 1.00); P-trend: 0.01; [underlined: Stroke Mortality,] HR (95% CI); Q1 (ref) vs Q2: 0.53 (0.29, 0.98); Q1 (ref) vs Q3: 0.61 (0.38, 0.99); Q1 (ref) vs Q4: 0.93 (0.57, 1.52); P-trend: 0.34; ALA; [underlined: Vascular Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.42; [underlined: Heart Disease Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.79; [underlined: Stroke Mortality,] HR (95% CI); Q1 (ref) vs Q2: 0.97 (0.63, 1.51); Q1 (ref) vs Q3: 1.00 (0.67, 1.47); Q1 (ref) vs Q4: 0.54 (0.30, 0.98); P-trend: 0.13; Total n-6 PUFA; [underlined: Vascular Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS P-trend: 0.48; [underlined: Heart Disease Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.61; [underlined: Stroke Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.57; LA; [underlined: Vascular Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.49; [underlined: Heart Disease Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.59; [underlined: Stroke Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.65; AA; [underlined: Vascular Mortality,] HR (95% CI); Q1 (ref) vs Q2: 0.90 (0.71, 1.15); Q1 (ref) vs Q3: 0.71 (0.57, 0.88); Q1 (ref) vs Q4: 0.81 (0.63, 1.05); P-trend: 0.01; [underlined: Heart Disease Mortality,] HR (95% CI); Q1 (ref) vs Q2: 0.87 (0.64, 1.18); Q1 (ref) vs Q3: 0.67 (0.53, 0.84); Q1 (ref) vs Q4: 0.80 (0.58, 1.11); P-trend: 0.02; [underlined: Stroke Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.54; n-6:n-3 PUFA Ratio; [underlined: Vascular Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.87; [underlined: Heart Disease Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.90; [underlined: Stroke Mortality,] HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: NS, P-trend: 0.39 | Key confounders [underlined: NOT] accounted for:; None; Key confounders accounted for: Sex, age, race/ethnicity, SES (education), TEI, smoking, alcohol intake, physical activity, family history of CVD or diabetes.; Additional model adjustments: Marital status, BMI, history of hypertension, history of diabetes, intake of vegetables, fruits, red meat, and SFA; Limitations:; - Only one, 24-hr recall used to assess diet; - No preregistered statistical analysis plan; Funding sources:; National Natural Science Foundation of China; Chinese Institute of Nutrition DSM Research Fund
Chiuve, 2012 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3417213/) ^152^; PCS, NHS (Nurse’s Health Study), U.S.; Baseline N=121,700 Analytic N=91,981 (Attrition: 24%); Participant characteristics at baseline:; - Age (Mean): 47 y (SD=7); - Sex (female): 100%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI ~24.4; Fat intake at baseline: NR; Blood lipids and BP at baseline:; - Hypertension: ~17%; - Hypercholesterolemia: ~6%; Summary of findings:; Higher SFA intake was significantly associated with greater risk of sudden cardiac death. Total PUFA, total n-3 PUFA, ALA, marine n-3 fats (EPA+DHA), n-6 PUFA and LA were associated with lower risk of sudden cardiac death. There were no associations with MUFA and sudden cardiac death. Replacement of carbohydrate with PUFAs, but not SFAs, was significantly associated with lower risk of sudden cardiac death. | Exposures:; - SFA (quintile; continuous, per 5% of total fat), Median (% total fat) (Q1 (ref) 32.8, Q2 35.7, Q3 38.0, Q4 40.3, Q5 43.9); - MUFA (quintile), Median (% total fat) (Q1 (ref) 35.9, Q2 37.8, Q3 39.2, Q4 40.8, Q5 43.7); - PUFA (quintile; continuous, per 5% of total fat), Median (% of total fat) (Q1 (ref) 10.5, Q2 13.6, Q3 15.8, Q4 17.8, Q5 20.7); - Total n-6 PUFA (quintile) Median (% total fat) (Q1 (ref) 8.2, Q2 11.4, Q3 13.6, Q4 15.6, Q5 18.6); - LA (quintile), Median (% total fat) (Q1 (ref) 7.8, Q2 11.0, Q3 13.2, Q4 15.2, Q5 17.9); - AA (quintile), Median (% total fat) (Q1 (ref) 0.15, Q2 0.19, Q3 0.22, Q4 0.26, Q5 0.33); - Total n-3 PUFAs (quintile), Median (%E) (Q1 (ref) 1.24, Q2 1.45, Q3 1.66, Q4 1.93, Q5 2.41); - ALA (quintile), Median (% total fat) (Q1 (ref) 1.14, Q2 1.31, Q3 1.46, Q4 1.64, Q5 2.10); - Marine n-3 fats (EPA + DHA) (quintile), Median (% total fat) (Q1 (ref) 0.05, Q2 0.10, Q3 0.17, Q4 0.27, Q5 0.51); - Isocaloric replacement of carbohydrate with SFA, total PUFAs, n-3 PUFAs or n-6 PUFAs; [underlined: Assessment method and timing]:; - Average of self-administered, validated 61-item FFQ; expanded to 116-items in 1984; - Assessed at baseline and every 4 years; Outcomes and assessment methods:; - Assessed during 30 y of follow-up; - [underlined: Incident sudden cardiac death (SCD; includes acute coronary thrombosis, severe coronary artery disease without myocardial necrosis):] reports from next of kin, National Death Index, death certificates, medical records; - [underlined: SCD:] 385 cases | [underlined: Incident SCD], RR (95% CI); [underlined: SFA]; Continuous: 1.11 (1.01, 1.23); Q1 (ref) vs Q2, Q3, Q4: All NS; Q1 (ref) vs Q5: 1.44 (1.04, 1.98); P linear trend=0.01; [underlined: MUFA]; Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P linear trend=0.29; [underlined: PUFA]; Continuous: 0.79 (0.69, 0.90); Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 0.54 (0.39, 0.74); Q1 (ref) vs Q4: 0.56 (0.40, 0.78); Q1 (ref) vs Q5: 0.57 (0.41, 0.78); P-trend: linear <0.001, non-linear <0.001; [underlined: Total n-3 PUFA]; Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 0.67 (0.50, 0.91); Q1 (ref) vs Q4: 0.45 (0.32, 0.64); Q1 (ref) vs Q5: 0.49 (0.35, 0.69); P-trend: linear <0.001, non-linear <0.001; [underlined: ALA]; Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 0.74 (0.55, 0.99); Q1 (ref) vs Q4: 0.53 (0.38, 0.74); Q1 (ref) vs Q5: 0.38 (0.25, 0.59); P linear trend<0.001; [underlined: Marine n-3 fats (EPA+DHA)]; Q1 (ref) vs Q2: 0.72 (0.54, 0.96); Q1 (ref) vs Q3: 0.63 (0.46, 0.86); Q1 (ref) vs Q4: 0.56 (0.40, 0.77); Q1 (ref) vs Q5: 0.50 (0.35, 0.70); P linear trend<0.001; [underlined: n-6 PUFA]; Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 0.63 (0.46, 0.86); Q1 (ref) vs Q4: 0.54 (0.39, 0.76); Q1 (ref) vs Q5: 0.61 (0.44, 0.85); P-trend: linear <0.001, non-linear <0.001; [underlined: LA]; Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 0.67 (0.49, 0.91); Q1 (ref) vs Q4: 0.60 (0.43, 0.83); Q1 (ref) vs Q5: 0.53 (0.38, 0.75); P-trend: linear <0.001, non-linear <0.001; [underlined: AA]; Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P linear trend: NS; Replacement of carbohydrate with:; [underlined: SFA:]; Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P linear trend: NS; [underlined: Total PUFAs:]; Q1 (ref) vs Q2: NS; Q3: 0.58 (0.42, 0.81); Q4: 0.56 (0.39, 0.79); Q5: 0.49 (0.33, 0.71); P linear trend<0.001; [underlined: Total n-3 PUFAs:]; Q1 (ref) vs Q2, Q3, Q4: All NS; Q5: 0.59 (0.40, 0.88); P linear trend=0.01; [underlined: Total n-6 PUFAs:]; Q1 (ref) vs Q2: NS; Q3: 0.68 (0.48, 0.97); Q4: NS; Q5: 0.63 (0.41, 0.96); P linear trend=0.02 | Key confounders [underlined: NOT] accounted for:; Sex, race/ethnicity, SES; Key confounders accounted for: Age, TEI, alcohol intake, physical activity, smoking, family history of MI; Additional model adjustments: Percent of energy from remaining fatty acids (replacement analyses only), Percent of energy from total fat, BMI, menopausal status, hormone therapy, aspirin use, use of multivitamins, use of vitamin E supplements, history of diabetes, hypertension, hypercholesterolemia, coronary heart disease and cancer at baseline; Limitations:; - Not all key confounders accounted for; - Bias due to missing data due to not accounting for missing data; - No preregistered statistical analysis plan; Funding sources:; American Heart Association, NIH
Li, 2015 (https://pubmed.ncbi.nlm.nih.gov/26429077/) ^183^; PCS, NHS (Nurse’s Health Study) and HPFS (Health Professionals Follow-Up Study), U.S.; Baseline N=173,230 Analytic N=127,536 (Attrition: 26%); Participant characteristics at baseline:; - 100% without prevalent CVD, diabetes or cancer; - Age: Women: ~46.5y, Men: ~53.2y; - Sex (female): ~66%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI ~24.8; Fat intake at baseline, Mean:; - MUFA: Women ~13.7%E, Men ~11.8%E; - PUFA: Women ~5.1%E, Men ~5.9 %E; Blood lipids and BP at baseline, Mean:; - TC (mg/dL): Women ~293, Men ~291; - Hypercholesterolemia: Women:~5%; Men: ~11%; - Hypertension: Women:~16%; Men: ~20%; Summary of findings:; Higher PUFA intake, compared to lower PUFA intake, was significantly associated with lower incidence of coronary heart disease. SFA and MUFA was not significantly associated with incidence of coronary heart disease. | Exposures:; - SFA (categorical, %E), Median (%E); - Q1 (ref; Men 7.4, Women 9.6); - Q2 (Men 9.2, Women 11.3); - Q3 (Men 10.4, Women 12.6); - Q4 (Men 11.6, Women 14.1); - Q5 (Men 13.6, Women 16.9); - MUFA (categorical, %E), Median (%E); - Q1 (ref; Men 9.0, Women 10.4); - Q2 (Men 10.9, Women 12.1); - Q3 (Men 12.1, Women 13.4); - Q4 (Men 13.3, Women 14.8); - Q5 (Men 15.1, Women 17.3); - PUFA (categorical, %E), Median (%E); - Q1 (ref; Men 4.4, Women 3.9); - Q2 (Men 5.2, Women 4.9); - Q3 (Men 5.8, Women 5.6); - Q4 (Men 6.4, Women 6.3); - Q5 (Men 7.5, Women 7.4); [underlined: Assessment method and timing]:; - Average of self-administered, validated FFQ; - Assessed at baseline and every 2 to 4 years thereafter; Outcomes and assessment methods:; - Assessed during 24 (HPFS) and 30 (NHS) y of follow-up; - [underlined: Incident total coronary heart disease (CHD; nonfatal MI, fatal CHD):] medical records, phone interview or letter (classified as probable), reports from next of kin, U.S. postal system, certificates from vital statistics departments and National Death Index, autopsy; - [underlined: Nonfatal MI:] 4,931 cases; - [underlined: CHD deaths:] 2,736 cases | [underlined: Incident CHD,] HR (95% CI); [underlined: SFA]; Men:; Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.16; Women:; Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.73; [underlined: MUFA]; Men:; Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.33; Women:; Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=0.22; [underlined: PUFA]; Men:; Q1 (ref) vs Q2, Q3, Q4: All NS; Q1 (ref) vs Q5: 0.83 (0.74, 0.94); P-trend=0.001; Women:; Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 0.78 (0.70, 0.88); Q1 (ref) vs Q4: 0.88 (0.78, 0.99); Q1 (ref) vs Q5: 0.76 (0.67, 0.87); P-trend=0.0003 | Key confounders [underlined: NOT] accounted for:; SES; Key confounders accounted for: Sex, age, race/ethnicity, TEI, alcohol intake, physical activity, smoking, family history of MI and diabetes; Additional model adjustments: Energy contribution from protein, cholesterol intake, BMI, use of vitamins and aspirin, presence of baseline hypertension and hypercholesterolemia, dietary intake of fruits and vegetables; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to excluding participants with diabetes; - Analyses did not account for co-exposure (other types of fats); - Potential risk of bias due to missing data; - No preregistered statistical analysis plan; Funding sources:; National Institutes of Health
Wang, 2016 (https://pubmed.ncbi.nlm.nih.gov/27379574/) ^218^; PCS, NHS (Nurse’s Health Study) and HPFS (Health Professionals Follow-up Study), U.S.; Baseline N=143,997 (NHS, n=92,468; HPFS, n=51,529) Analytic N=126,233 (NHS, n=83,349; HPFS, n=42,884) (Attrition: 12%); Participant characteristics at baseline:; - 100% without prevalent CVD, diabetes or cancer; - Age: NHS: ~46y; HPFS: ~53y; - Sex (female): 66% (NHS 100%, HPFS 0%); - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI NHS ~24, HPFS: ~25; Fat intake at baseline, Mean:; - SFA: Women ~12%E, Men ~10%E; - MUFA: Women ~13%E, Men ~12%E; - PUFA: Women ~6%E, Men ~6E; - Cholesterol: Women ~300 mg/d, Men ~295 mg/d; Blood lipids and BP at baseline:; - Hypercholesterolemia: Women ~6%; Men ~11%; - Hypertension: Women ~16%; Men ~20%; Summary of findings:; Higher intake of SFAs and marine n-3 fats (DHA+EPA) were significantly associated with higher incidence of CVD. Higher intakes of unsaturated fatty acids, MUFAs, PUFAs, and replacement of total carbohydrate with unsaturated fatty acids, and PUFA were significantly associated with lower incidence of CVD. Replacement of total carbohydrates with MUFA was significantly associated with lower incidence of CVD in women only. | Exposures:; - SFA (quintiles), Median (%E) (NHS: Q1 8.2, Q2 10.2, Q3 11.8, Q4 13.5, Q5 16.5; HPFS: Q1 7.1 Q2 9.0, Q3 10.2, Q4 11.5, Q5 13.5,); - UFA (quintiles), Median (%E) (NHS: Q1 14.2, Q2 16.8, Q3 18.7, Q4 20.6, Q5 23.8; HPFS: Q1 13.7, Q2 16.3, Q3 18.0, Q4 19.7, Q5 22.3); - MUFA (quintiles), Median (%E) (NHS: Q1 9.4, Q2 11.4, Q3 12.8, Q4 14.4, Q5 17.2; HPFS: Q1 8.9, Q2 10.8, Q3 12.1, Q4 13.3, Q5 15.3); - PUFA (quintiles), Median (%E) (NHS: Q1 4.2, Q2 5.0, Q3 5.6, Q4 6.3, Q5 7.5; HPFS: Q1 4.4, Q2 5.2, Q3 5.8, Q4 6.5, Q5 7.7); - n-6 PUFA, n-3 PUFA, and replacement presented on following 2 pages; [underlined: Assessment method and timing]:; - Average of self-administered, validated, semi-quantitative FFQ; - Assessed at baseline and every 2-4 years thereafter; Outcomes and assessment methods:; - Assessed during 26 (HPFS) and 32 (NHS) y of follow-up; - [underlined: Cardiovascular disease (CVD) mortality:] National Death Index, reports from family members or postal authorities, death certificates and medical records; Exposures:; - Total n-6 PUFAs (quintiles), Median (%E) (NHS: Q1 3.4, Q2 4.3, Q3 4.9, Q4 5.5, Q5 6.7; HPFS: Q1 3.7, Q2 4.5, Q3 5.1, Q4 5.8, Q5 6.9); - LA (quintiles), Median (%E) (NHS: Q1 3.3, Q2 4.2, Q3 4.8, Q4 5.4, Q5 6.5; HPFS: Q1 3.6, Q2 4.4, Q3 5.0, Q4 5.6, Q5 6.7); - AA (quintiles), Median (%E) (NHS: Q1 0.05, Q2 0.06, Q3 0.07, Q4 0.09, Q5 0.11; HPFS: Q1 0.05, Q2 0.06, Q3 0.07, Q4 0.09, Q5 0.11); - Total n-3 PUFAs (quintiles), Median (%E) (NHS: Q1 0.48, Q2 0.57, Q3 0.63, Q4 0.72, Q5 0.88; HPFS: Q1 0.46, Q2 0.57, Q3 0.65, Q4 0.75, Q5 0.94); - ALA (quintiles), Median (%E) (NHS: Q1 0.41, Q2 0.48, Q3 0.53, Q4 0.59, Q5 0.70; HPFS: Q1 0.38, Q2 0.45, Q3 0.50, Q4 0.56, Q5 0.68); - Marine n-3 fats (DHA+EPA, includes fish, chicken or turkey, shrimp, lobster, scallops) (quintiles), Median (%E) (NHS: Q1 0.03, Q2 0.05, Q3 0.08, Q4 0.12, Q5 0.21; HPFS: Q1 0.04, Q2 0.08, Q3 0.12, Q4 0.18, Q5 0.31); - Replacement presented on following page.; Exposures:; - Isocaloric replacement of total carbohydrate with:; - SFA (5%E); - UFA (5%E); - MUFA (5%E); - PUFA (5%E); - Total n-6 PUFA (2%E); - LA (2%E); - Total n-3 PUFA (0.3%E); - AA (0.3%E); - ALA (0.3%E); - Marine n-3 fats (0.3%E); - SFA, UFA, MUFA, PUFA, n-6 PUFA, and n-3 PUFA presented on previous pages. | [underlined: CVD mortality,] HR (95% CI); [underlined: SFA]; NHS: P-trend=0.02; Q1 (ref) vs Q2: 1.15 (1.04, 1.26); Q1 (ref) vs Q3: 1.17 (1.04, 1.31); Q1 (ref) vs Q4: 1.18 (1.03, 1.34); Q1 (ref) vs Q5: 1.21 (1.03, 1.41); HPFS: P-trend=NS; Q1 (ref) vs Q2, Q3, Q4, Q5: NS,; [underlined: UFA]; NHS: P-trend<0.001; Q1 (ref) vs Q2: 0.91 (0.83, 1.00); Q1 (ref) vs Q3: 0.84 (0.75, 0.93); Q1 (ref) vs Q4: 0.76 (0.67, 0.85); Q1 (ref) vs Q5: 0.68 (0.60, 0.78); HPFS: P-trend=0.002; Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 0.86 (0.77, 0.96); Q1 (ref) vs Q4: 0.87 (0.77, 0.98); Q1 (ref) vs Q5: 0.83 (0.73, 0.94); [underlined: MUFA]; NHS: P-trend=0.001; Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 0.88 (0.78, 0.99); Q1 (ref) vs Q4: 0.82 (0.72, 0.95); Q1 (ref) vs Q5: 0.79 (0.67, 0.94); HPFS: P-trend=NS; Q1 (ref) vs Q2, Q3, Q4, Q5: NS,; [underlined: PUFA]; NHS: P-trend<0.001; Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 0.89 (0.80, 0.98); Q1 (ref) vs Q4: 0.85 (0.76, 0.94); Q1 (ref) vs Q5: 0.80 (0.71, 0.89); HPFS: P-trend<0.001; Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 0.88 (0.79, 0.98); Q1 (ref) vs Q4: 0.80 (0.72, 0.90); Q1 (ref) vs Q5: 0.83 (0.74, 0.94); [underlined: Total n-6 PUFAs]; NHS: P-trend=0.02; Q1 (ref) vs Q2: 0.88 (0.80, 0.98); Q1 (ref) vs Q3: 0.88 (0.79, 0.98); Q1 (ref) vs Q4: 0.82 (0.73, 0.92); Q1 (ref) vs Q5: 0.84 (0.74, 0.96); HPFS: P-trend<0.001; Q1 (ref) vs Q2: 0.90 (0.81, 0.99); Q1 (ref) vs Q3: 0.84 (0.75, 0.94); Q1 (ref) vs Q4: 0.80 (0.71, 0.91); Q1 (ref) vs Q5: 0.78 (0.68, 0.89); [underlined: LA]; NHS: P-trend=0.002; Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 0.87 (0.78, 0.97); Q1 (ref) vs Q4: 0.85 (0.75, 0.95); Q1 (ref) vs Q5: 0.81 (0.71, 0.93); HPFS: P-trend<0.001; Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 0.86 (0.77, 0.95); Q1 (ref) vs Q4: 0.78 (0.69, 0.87); Q1 (ref) vs Q5: 0.75 (0.66, 0.86); [underlined: AA]; NHS and HPFS: P-trend=NS; Q1 (ref) vs Q2, Q3, Q4, Q5: NS; [underlined: Total n-3 PUFAs]; NHS and HPFS: P-trend=NS; Q1 (ref) vs Q2, Q3, Q4, Q5: NS; [underlined: ALA]; NHS: P-trend=NS; Q1 (ref) vs Q2: 0.89 (0.81, 0.99); Q1 (ref) vs Q3, Q4, Q5: All NS; HPFS: P-trend=NS; Q1 (ref) vs Q2, Q3, Q4, Q5: NS; [underlined: Marine n-3 fats (DHA+EPA)]; NHS: P-trend=NS; Q1 (ref) vs Q2, Q3, Q4, Q5: NS; HPFS: P-trend=0.01; Q1 (ref) vs Q2, Q3: All NS; Q1 (ref) vs Q4: 1.15 (1.03, 1.28); Q1 (ref) vs Q5: 1.16 (1.03, 1.30); Isocaloric replacement of total carbohydrate with:; NHS:; SFA: 1.11 (1.02, 1.22); UFA: 0.82 (0.76, 0.87); MUFA: 0.84 (0.75, 0.93); PUFA: 0.72 (0.62, 0.85); Total n-6 PUFAs: 0.91 (0.84, 0.98); LA: 0.88 (0.81, 0.96); AA: NS; Total n-3 PUFAs: NS; ALA: NS; Marine n-3 fats (DHA+EPA): NS; HPFS:; SFA: NS; UFA: 0.90 (0.84, 0.96); MUFA: NS; PUFA: 0.73 (0.61, 0.87); Total n-6 PUFAs: 0.86 (0.79, 0.93); LA: 0.82 (0.75, 0.89); AA: NS; Total n-3 PUFAs: NS; ALA: NS; Marine n-3 fats (DHA+EPA): 1.16 (1.04, 1.31) | Key confounders [underlined: NOT] accounted for:; None; Key confounders accounted for: Sex, age, race/ethnicity, SES, TEI, alcohol intake, physical activity, smoking, family history of MI and diabetes; Additional model adjustments: BMI, multivitamin use, vitamin E supplement use, current aspirin use, family history of cancer, history of hypertension, history of hypercholesterolemia, dietary cholesterol and percentage of energy intake from dietary proteins, menopausal status and hormone use in women, % of energy intake from remaining fatty acids; Limitations:; - Potential selection bias due to excluding participants with diabetes; - No preregistered statistical analysis plan; Funding sources:; National Institutes of Health
Zong, 2016 (https://pubmed.ncbi.nlm.nih.gov/27881409/) ^228^; PCS, NHS (Nurse’s Health Study) and HPFS (Health Professionals Follow-up Study), U.S.; Baseline N=173,229 Analytic N=115,782 (Attrition: 33%); Participant characteristics at baseline:; - 100% without prevalent CVD, diabetes or cancer; - Age: Women 30-55y Men: 40-75y; - Sex (female): NHS: 100%, HPFS: 0%; - Race/ethnicity: ~97% white; - SES: NR (“homogeneous … socioeconomic status”); - Anthropometry: BMI ~25; Fat intake at baseline, Mean:; - SFAs: 12:0, 14:0, 16:0, 18:0 accounted for 8.8-10.7%E; - MUFAs: ~12%E; - PUFAs: ~6.3%E; - Trans fat: Women ~2.0%E, Men ~1.3%E; Blood lipids and BP at baseline:; - Hypertension: women ~20%; men ~20%; - Hypercholesterolemia: women ~7%; men ~10%; Summary of findings:; Higher intake of SFA (sum of C12:0-C18:0) was significantly associated with higher incidence of coronary heart disease in men and women. This was not significant with shorter-chain SFA (sum of C4:0-C10:0). Isocaloric replacement of 12:0-18:0 SFA by PUFA, whole-grains, and plant proteins was significantly associated with a reduced risk of CHD. | Exposures:; - SFA (sum of C4:0-C10:0) (quintile, %E), Median (%E); - Q1 (ref; Women 0.30, Men 0.21); - Q2 (Women 0.41, Men 0.32); - Q3 (Women 0.50, Men 0.41); - Q4 (Women 0.61, Men 0.52); - Q5 (Women 0.82, Men 0.73); - SFA (sum of C12:0-C18:0) (quintile, %E), Median (%E); - Q1 (ref; Women 7.58, Men 6.71); - Q2 (Women 9.00, Men 8.42); - Q3 (Women 9.96, Men 9.57); - Q4 (Women 10.98, Men 10.72); - Q5 (Women 12.64, Men 12.49); - Replacement of SFA (1%E) with:; - PUFA; - MUFA; - Whole-grain carbohydrate; - Plant protein; [underlined: Assessment method and timing]:; - Average of self-administered, validated FFQ; - Assessed at baseline and every 2 to 4 years thereafter; Outcomes and assessment methods:; - Assessed during Mean of 25.8 (NHS) and 21.2 (HPFS) y of follow-up; - [underlined: Incident total coronary heart disease (CHD; nonfatal MI, fatal CHD):] medical records, phone interview or letter (classified as probable), reports from next of kin, U.S. postal system, certificates from vital statistics departments and National Death Index, autopsy; - [underlined: Nonfatal MI:] 4,348 cases; - [underlined: CHD deaths:] 2,687 cases | [underlined: Incident CHD,] HR (95% CI); [underlined: SFA (4:0-10:0)]; NHS (women):; Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=NS; HPFS (men):; Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=NS; [underlined: SFA (12:0-18:0)]; NHS (women):; Q1 (ref) vs; Q2, Q3: All NS; Q4: 1.14 (1.01, 1.28); Q5: 1.17 (1.04, 1.31); P=0.01; HPFS (men):; Q1 (ref) vs; Q2, Q3: All NS; Q4: 1.20 (1.08, 1.32); Q5: 1.19 (1.08, 1.32); P-trend<0.001; Replacement of SFA (C12:0-C18:0) with*:; NHS (women):; PUFA: 0.89 (0.84, 0.95), <0.001; MUFA: NS; Whole-grain carbohydrate: 0.94 (0.89, 0.99), P=0.03; Plant protein: NS; HPFS (men):; PUFA: 0.95 (0.91, 0.99), P=0.02; MUFA: NS; Whole-grain carbohydrate: 0.96 (0.92, 1.00), P=0.04; Plant protein: 0.93 (0.89, 0.98), P=0.01; *Similar results were found when excluding participants with probable fatal CHD | Key confounders [underlined: NOT] accounted for:; SES; Key confounders accounted for: Sex, age, race/ethnicity, TEI, alcohol intake, physical activity, smoking, family history of MI; Additional model adjustments: Menopausal status and postmenopausal hormone use (women), current aspirin use, multivitamin use, baseline hypertension, baseline hypercholesterolemia, BMI; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to excluding participants with diabetes; - Analyses did not account for co-exposure (other types of fats); - No preregistered statistical analysis plan; Funding sources:; NIH, NHLBI
Zong, 2018 (https://pubmed.ncbi.nlm.nih.gov/29566185/) ^227^; NHS (Nurse’s Health Study) and HPFS (Health Professionals Follow-up Study), U.S.; Baseline N=173,229 (NHS, N=121,700; HPFS, N=51,529) Analytic N=93,384 (NHS, N=63,442; HPFS: n=29,942) (Attrition: 46%); Participant characteristics at baseline:; - 100% without prevalent CHD, cancer or diabetes; - Age: Women: ~68y, Men: ~67y; - Sex (female): NHS: 100%, HPFS: 0%; - Race/ethnicity: NHS: ~98% White, HPFS: ~96% White; - SES: NR; - Anthropometry: BMI: NHS:~26, HPFS:~24; Fat intake at baseline, Mean (SD):; - SFAs (%E): NHS: ~10, HPFS: ~10; - MUFAs from plants (%E): NHS: 5.8, HPFS: 6.3; - MUFAs from animals (%E): NHS: 5.4, HPFS: 5.5; - PUFAs (%E):NHS: ~6, HPFS: ~6; - Trans fat (%E): NHS: ~1.4, HPFS: ~1.5; Blood lipids and BP at baseline: NR; Summary of findings:; Higher intake of total MUFAs was associated with lower incidence of CHD when comparing the lowest to second lowest quintiles of intake in men only. MUFAs from plants were not associated with incidence of CHD. MUFAs from animal sources was associated with higher incidence of CHD in women and men. Significantly lower CHD risk was observed when SFAs or refined carbohydrates were replaecd by MUFAs from plant sources but not MUFAs from animal sources. | Exposures:; - Total MUFAs (%e, quintile), Median (Q1: NHS 8.7, HPFS: 8.8; Q2: NHS 10.5, HPFS: 10.8; Q3: NHS 11.7, HPFS: 12.1; Q4: NHS 13.0, HPFS: 13.3; Q5: NHS 14.9, HPFS: 15.3); - Total MUFAs from plants (vegetable cooking oils, breads and cereals, fruit, vegetables, legumes, nuts, seeds) (%e, quintile), Median (Q1: NHS 3.7, HPFS: 4.0; Q2: NHS 4.9, HPFS: 5.2; Q3: NHS 5.8, HPFS: 6.1; Q4: NHS 6.8, HPFS: 7.1; Q5: NHS 8.6, HPFS: 8.8); - Total MUFAs from animals (animal fats for cooking, dairy products, eggs, poultry, processed and unprocessed red meats, fish) (%e, quintile), Median (Q1: NHS 3.4, HPFS: 3.2; Q2: NHS 4.5, HPFS: 4.5; Q3: NHS 5.3, HPFS: 5.4; Q4: NHS 6.1, HPFS: 6.4; Q5: NHS 7.5, HPFS: 8.0); - Replacement of SFAs (%5E) with:; - MUFAs from plants or animals; - Replacement of MUFAs from animals (5%E) with:; - MUFAs from plants; - Replacement of SFAs+MUFAs from animals (5%E) with:; - MUFAs from plants; - Replacement of refined CHO (5%E) with:; - MUFAs from plants or animals; [underlined: Assessment method and timing]:; - Average of self-administered, validated FFQ; - Assessed at baseline (1990) and every 2 years; Outcomes and assessment methods:; - Assessed during ~22 y of follow-up; - [underlined: Incident coronary heart disease (CHD; nonfatal] [underlined: MI, fatal CHD):] medical records, follow-up questionnaires, phone interview or letter, reports from next of kin, U.S. postal authorities, National Death Index, autopsy reports | [underlined: Incident CHD,] HR (95% CI); [underlined: Total MUFAs]; NHS (women): P-trend=NS; Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; HPFS: (men): P-trend=NS; Q1 (ref) vs Q2: 0.82 (0.71, 0.94); Q1 (ref) vs Q3, Q4, Q5: All NS; [underlined: MUFAs from plants]; NHS (women): P-trend=0.04; Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; HPFS: (men): P-trend=NS; Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; [underlined: MUFAs from animals]; NHS (women): P-trend=NS; Q1 (ref) vs Q2: NS; Q1 (ref) vs Q3: 1.29 (1.09, 1.51); Q1 (ref) vs Q4: 1.20 (1.00, 1.43); Q1 (ref) vs Q5: NS; HPFS (men): P-trend=0.004; Q1 (ref) vs Q2, Q3: NS; Q1 (ref) vs Q4: 1.22 (1.04, 1.44); Q1 (ref) vs Q5: 1.26 (1.04, 1.54); [underlined: Replacement of SFAs with:]; MUFAs from plants: NHS: NS; HPFS: NS; MUFAs from animals: NHS: NS, HPFS: NS; [underlined: Replacement of MUFAs from animals with:]; MUFAs from plants:; NHS: 0.73 (0.58, 0.92), P=0.007; HPFS: 0.77 (0.63, 0.93), P=0.007; [underlined: Replacement of SFA+MUFAs from animals with:]; MUFAs from plants:; NHS: 0.79 (0.68, 0.92), P=0.002; HPFS: 0.82 (0.71, 0.94), P=0.005; [underlined: Replacement of refined carbohydrates with:]; MUFAs from plants: NHS: NS; HPFS: NS; MUFAs from animals: NHS: NS; HPFS: NS | Key confounders [underlined: NOT] accounted for:; SES; Key confounders accounted for: Sex, age, race/ethnicity, SES, TEI, alcohol intake, physical activity, smoking, family history of MI and diabetes; Additional model adjustments: Menopausal status and postmenopausal hormone use (NHS only), current aspirin use, multivitamin use, baseline hypertension, baseline hypercholesterolemia, BMI, intakes of fruit and vegetables, SFA intake; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to excluding participants with diabetes; - Analyses did not account for co-exposure (other types of fats); - Potential missing data bias due to not accounting for missing data; - No preregistered statistical analysis plan; Funding sources:; National Institutes of Health, Unilever R&D, California Walnut Commission and Metagenics; National Institute of Environmental Health Sciences
Reedy, 2014 (https://www.ncbi.nlm.nih.gov/pubmed/24572039) ^199^; PCS, NIH-AARP Diet and Health Study, U.S.; Baseline N=566,398 Analytic N=424,662 (Attrition: 25%); Participant characteristics at baseline:; - AARP members 50-71y of age at baseline without previous cancer or heart disease; - Age: ~62y; - Sex (female): 43%; - Race/ethnicity: ~91% White; - SES: College graduate or postgraduate, ~39%; - Anthropometry: BMI, ~26; Fat intake at baseline:; - NR; Blood lipids and BP at baseline:; - NR; Summary of findings:; In men, higher intake of PUFA and EPA+DHA, and a higher PUFA+MUFA:SFA and MUFA:SFA at ~62y of age was significantly associated with lower risk of CVD mortality over 15y of follow-up. In women, only EPA+DHA intake and the PUFA+MUFA:SFA intake ratio were significantly associated with lower risk of CVD mortality. | - PUFA (continuous; per 1 point increase in AHEI-2010 component score); - Criteria for minimum score: ≤2%E; - Criteria for maximum score: ≥10%E; - EPA+DHA (continuous; per 1 point increase in AHEI-2010 component score); - Criteria for minimum score: 0 mg/d; - Criteria for maximum score: 250 mg/d; - PUFA+MUFA:SFA ratio (continuous; per 1 point increase in HEI-2010 component score); - Criteria for minimum score: <1.2; - Criteria for maximum score: ≥2.5; - MUFA:SFA ratio (continuous; per 1 point increase in aMED component score); - Criteria for minimum score: Less than median; - Criteria for maximum score: Median or greater; [underlined: Assessment method and timing]:; - Validated, self-administered, 124-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 15y of follow-up; - [underlined: CVD Mortality:] Obtained via linkage to Social Security Administration Death Master File and National Death Index Plus; - [underlined: CVD Mortality:] 23,502 cases (15,497 men, 8,005 women) | PUFA; [underlined: Total CVD Mortality,] HR (95% CI); Men: 0.989 (0.982, 0.996); Women: 0.995 (0.986, 1.005); EPA+DHA; [underlined: Total CVD Mortality,] HR (95% CI); Men: 0.985 (0.979, 0.991); Women: 0.983 (0.974, 0.993); PUFA+MUFA:SFA ratio; [underlined: Total CVD Mortality,] HR (95% CI); Men: 0.984 (0.978, 0.989); Women: 0.992 (0.985, 0.9996); MUFA:SFA ratio; [underlined: Total CVD Mortality,] HR (95% CI); Men: 0.937 (0.908, 0.968); Women: 1.003 (0.960, 1.049) | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: Marital status, BMI, diabetes, hormone replacement therapy (women), modified total index score minus component of interest; Limitations:; - Not all key confounders accounted for; - Analyses did not account for co-exposure (other types of fats); - No preregistered statistical analysis plan; Funding sources:; NR
Zhang, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/30019399) ^223^; PCS, NIH-AARP Diet and Health Study, U.S.; Baseline N=567,169 Analytic N=421,309 (Attrition: 26%); Participant characteristics at baseline:; - AARP members 50-71y of age without cancer, heart disease, stroke, or end-stage renal disease, and not in “poor health” at baseline; - Age: ~62y; - Sex (female): 42.9%; - Race/ethnicity: [underlined: Men], 92% White, 3% Black, 2% Hispanic, 1% Asian; [underlined: Women], 89% White, 6% Black, 2% Hispanic, 1% Asian; - SES: Annual household income, [underlined: Men] ~$50,500, [underlined: Women], ~$46,800; College graduate or postgraduate, 46% of [underlined: men], 31% of [underlined: women]; - Anthropometry: BMI, [underlined: Men] ~26.6, [underlined: Women] ~25.6; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - History of high cholesterol: ~28% of men, ~32% of women; - History of hypertension: ~22% of men, ~22% of women; Summary of findings:; In men and women, higher intake of long chain n-3 PUFA at ~62y of age was associated with lower risk of cardiovascular disease mortality (both heart disease and stroke/cerebrovascular mortality) over ~16y of follow-up. | Exposures:; - Long chain n-3 PUFA (EPA, DHA, and DPA; quintiles; g/d); - Q1 (ref; Men: ≤0.04, Women: ≤0.03); - Q2 (Men: 0.05-0.07, Women: 0.04-0.06); - Q3 (Men: 0.08-0.10, Women: 0.07-0.09); - Q4 (Men: 0.11-0.17, Women: 0.10-0.15); - Q5 (Men: ≥0.18, Women: ≥0.16); [underlined: Assessment method and timing]:; - Validated, self-administered, semi-quantitative 124-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~16y of follow-up; - [underlined: CVD Mortality (heart disease and stroke/cerebrovascular mortality):] Obtained via linkage to Social Security Administration Death Master File and National Death Index Plus; - [underlined: Total CVD Mortality:] 14,824 cases in men, 7,541 cases in women; - [underlined: Heart Disease Mortality:] 12,636 cases in men, 5,939 cases in women; - [underlined: Stroke or Cerebrovascular Mortality:] 2,188 cases in men, 1,602 cases in women | Long chain n-3 PUFA; [underlined: Total CVD Mortality,] HR (95% CI); Men: P-trend: <0.0001; Q1 (ref) vs Q2: 0.92 (0.87, 0.97); Q1 (ref) vs Q3: 0.88 (0.83, 0.93); Q1 (ref) vs Q4: 0.87 (0.82, 0.92); Q1 (ref) vs Q5: 0.85 (0.80, 0.90); Women: P-trend: <0.0001; Q1 (ref) vs Q2: 0.93 (0.86, 1.00); Q1 (ref) vs Q3: 0.88 (0.81, 0.95); Q1 (ref) vs Q4: 0.87 (0.80, 0.94); Q1 (ref) vs Q5: 0.82 (0.75, 0.90); [underlined: Heart Disease Mortality,] HR (95% CI); Men: P-trend: 0.0004; Q1 (ref) vs Q2: 0.92 (0.87, 0.97); Q1 (ref) vs Q3: 0.89 (0.84, 0.94); Q1 (ref) vs Q4: 0.89 (0.84, 0.95); Q1 (ref) vs Q5: 0.90 (0.85, 0.95); Women: P-trend: 0.0029; Q1 (ref) vs Q2: 0.94 (0.87, 1.01); Q1 (ref) vs Q3: 0.90 (0.83, 0.98); Q1 (ref) vs Q4: 0.91 (0.84, 0.99); Q1 (ref) vs Q5: 0.87 (0.80, 0.95); [underlined: Stroke or Cerebrovascular Mortality,] HR (95% CI); Men: P-trend: 0.0005; Q1 (ref) vs Q2: 0.97 (0.86, 1.11); Q1 (ref) vs Q3: 0.92 (0.80, 1.06); Q1 (ref) vs Q4: 0.89 (0.77, 1.02); Q1 (ref) vs Q5: 0.78 (0.68, 0.90); Women: P-trend: 0.0029; Q1 (ref) vs Q2: 0.94 (0.81, 1.09); Q1 (ref) vs Q3: 0.86 (0.73, 1.01); Q1 (ref) vs Q4: 0.82 (0.70, 0.97); Q1 (ref) vs Q5: 0.80 (0.67, 0.95); Statistically significant interactions between long chain n-3 PUFA intake and BMI (men), alcohol intake (men and women), diabetes (women), physical activity (women), red meat consumption (men and women), and SFA intake (men; lower risk with SFA intake below median) were detected | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: BMI, marital status, intake of red meat, SFA, vegetables and fruit, multivitamin use, aspirin use, history of diabetes, history of hypertension, history of high cholesterol, intake of ALA, n-6 PUFA, MUFA, and trans-FA; Women: hormones use.; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Zhejiang Provincial Natural Science Foundation of China; National Natural Science Foundation of China; Intramural Research Program of the NIH, NCI; China National Program for Support of Top-notch Young Professionals
Zhuang, 2019a (https://pubmed.ncbi.nlm.nih.gov/30636521/) ^226^; PCS, NIH-AARP Diet and Health Study, U.S.; Baseline N=567,169 Analytic N=521,120 (Attrition: 8%); Participant characteristics at baseline:; - AARP members 50-71y of age at baseline; - Age: ~63y; - Sex (female): 41.2%; - Race/ethnicity: ~91% White, ~4% Black, ~2% Hispanic, ~1% Asian;; - SES: Annual household income, ~$48,700; College graduate or postgraduate, ~39%; - Anthropometry: BMI, ~26; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - History of hypercholesterolemia: ~26%; - History of hypertension: ~23%; Summary of findings:; In men and women, higher intake of SFA at ~63y of age was associated with higher risk of CVD mortality during ~16y of follow-up when replacing CHO. Replacing SFA intake with total MUFA, plant-MUFA, total PUFA, marine n-3 PUFA, n-6 PUFA, or LA intake was associated with lower risk of CVD mortality. Replacing SFA intake with AA intake was associated with higher risk of CVD mortality. Higher intake of plant-MUFA, total PUFA, marine n-3 PUFA, total n-6 PUFA, and ALA were associated with lower risk of CVD mortality when replacing CHO. Higher intake of animal-MUFA and AA were associated with higher risk of CVD mortality when replacing CHO. The n-6/n-3 PUFA ratio was not associated with CVD mortality. | Exposures (all continuous and quintiles:; - SFA (%E); - Q1 (≤6.89), Q2 (6.89-8.50), Q3 (8.50-9.98), Q4 (9.98-11.78), Q5 (≥11.78); - MUFA (%E); - Q1 (≤8.73), Q2 (8.73-10.62), Q3 (10.62-12.23), Q4 (12.23-14.03), Q5 (≥14.03); - Animal-MUFA (%E); - Q1 (≤4.19), Q2 (4.19-5.43), Q3 (5.43-6.56), Q4 (6.56-7.92), Q5 (≥7.92); - Plant-MUFA (%E); - Q1 (≤4.19), Q2 (4.19-5.43), Q3 (5.43-6.56), Q4 (6.56-7.92), Q5 (≥7.92); - For PUFAs, please see next page; [underlined: Assessment method and timing]:; - Validated, self-administered, 124-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~16y of follow-up; - [underlined: CVD Mortality:] Obtained via linkage to Social Security Administration Death Master File and National Death Index Plus; - [underlined: CVD Mortality:] 38,747 cases; Exposures (all continuous and quintiles, replacing CHO unless otherwise noted):; - PUFA (%E); - Q1 (≤5.20), Q2 (5.20-6.27), Q3 (6.27-7.29), Q4 (7.29-8.64), Q5 (≥8.64); - Total n-3 PUFA (%E); - Q1 (≤0.54), Q2 (0.54-0.63), Q3 (0.63-0.73), Q4 (0.73-0.87), Q5 (≥0.87); - ALA (%E); - Q1 (≤0.48), Q2 (0.48-0.58), Q3 (0.58-0.67), Q4 (0.67-0.80), Q5 (≥0.80); - Marine n-3 PUFA (EPA+DHA; %E); - Q1 (≤0.02), Q2 (0.02-0.03), Q3 (0.03-0.05), Q4 (0.05-0.08), Q5 (≥0.08); - Total n-6 PUFA (%E); - Q1 (≤4.57), Q2 (4.57-5.56), Q3 (5.56-6.49), Q4 (6.49-7.73), Q5 (≥7.73); - LA (%E); - Q1 (≤4.53), Q2 (4.53-5.50), Q3 (5.50-6.44), Q4(6.44-7.67), Q5(≥7.67); - AA (%E); - Q1 (≤0.03), Q2 (0.03-0.04), Q3 (0.04-0.05), Q4 (0.05-0.07), Q5 (≥0.07); - n-6/n-3 PUFA ratios; - Q1 (≤7.43), Q2 (7.43-8.29), Q3 (8.29-9.08), Q4 (9.08-10.14), Q5 (≥10.14) | SFA (Replacing CHO); [underlined: Total CVD Mortality,] HR (95% CI); Continuous: 1.07 (1.05, 1.09); Q1 (ref) vs Q2: 1.11 (1.06, 1.15); Q1 (ref) vs Q3: 1.15 (1.10, 1.20); Q1 (ref) vs Q4: 1.23 (1.17, 1.29); Q1 (ref) vs Q5: 1.27 (1.21, 1.34); P-trend: <0.0001; Replacement of SFA with Other FAs; [underlined: Total CVD Mortality,] HR (95% CI); MUFA (per 5%): 0.87 (0.81, 0.94); P-MUFA (per 5%): 0.90 (0.84, 0.97); Total PUFA (per 5%): 0.85 (0.82, 0.88); Marine n-3 PUFA: 0.96 (0.94, 0.99); n-6 PUFA (per 2%): 0.94 (0.92, 0.96); LA: 0.94 (0.92, 0.96); AA: 1.15 (1.08, 1.22); A-MUFA (per 5%), n-3 PUFA (per 0.3%), and ALA: All NS; MUFA (Replacing CHO); [underlined: Total CVD Mortality,] HR (95% CI); MUFA: Continuous: NS; Q1 (ref) vs Q2: 0.95 (0.91, 1.00); Q1 (ref) vs Q3: 0.91 (0.86, 0.96); Q1 (ref) vs Q4: 0.92 (0.87, 0.98); Q1 (ref) vs Q5: 0.95 (0.88, 1.01); P-trend: 0.42; Animal-MUFA: Continuous: 1.04 (1.02, 1.07); Q1 (ref) vs Q2: 1.02 (0.98, 1.06); Q1 (ref) vs Q3: 0.99 (0.94, 1.04); Q1 (ref) vs Q4: 1.06 (1.00, 1.11); Q1 (ref) vs Q5: 1.09 (1.03, 1.16); P-trend: 0.0015; Plant-MUFA: Continuous: NS; Q1 (ref) vs Q2: 0.99 (0.96, 1.03); Q1 (ref) vs Q3: 0.93 (0.89, 0.97); Q1 (ref) vs Q4: 0.94 (0.89, 0.97)Q1 (ref) vs Q5: 0.94 (0.89, 0.99); P-trend: 0.015; Sensitivity analyses produced similar results. See Zhuang, 2019 for details.; PUFAs (Replacing CHO); [underlined: Total CVD Mortality,] HR (95% CI); Total PUFA: Continuous: NS; Q1 (ref) vs Q2: 0.97 (0.94, 1.01); Q1 (ref) vs Q3: 0.95 (0.92, 0.99); Q1 (ref) vs Q4: 0.93 (0.90, 0.97); Q1 (ref) vs Q5: 0.94 (0.90, 0.98); P-trend: 0.0074; Total n-3 PUFA: Continuous: NS; Q1 (ref) vs Q2, Q3, Q4, and Q5: All NS; P-trend: 0.95; ALA: Continuous: NS; Q1 (ref) vs Q2, Q3, Q4, and Q5: All NS; P-trend: 0.16; Marine n-3 PUFA: Continuous: 0.98 (0.97, 0.99); Q1 (ref) vs Q2: 0.96 (0.93, 0.99); Q1 (ref) vs Q3: 0.96 (0.93, 0.99); Q1 (ref) vs Q4: 0.93 (0.90, 0.96); Q1 (ref) vs Q5: 0.90 (0.87, 0.94); P-trend: <0.0001; Total n-6 PUFA: Continuous: NS; Q1 (ref) vs Q2: 0.97 (0.93, 1.00); Q1 (ref) vs Q3: 0.94 (0.90, 0.98); Q1 (ref) vs Q4: 0.92 (0.88, 0.97); Q1 (ref) vs Q5: 0.93 (0.88, 0.98); P-trend: 0.0065; LA: Continuous: NS; Q1 (ref) vs Q2: 0.96 (0.93, 1.00); Q1 (ref) vs Q3: 0.93 (0.89, 0.98); Q1 (ref) vs Q4: 0.92 (0.87, 0.96); Q1 (ref) vs Q5: 0.92 (0.87, 0.98); P-trend: 0.0038; AA: Continuous: 1.03 (1.02-1.05); Q1 (ref) vs Q2: 1.02 (0.98, 1.05); Q1 (ref) vs Q3: 1.03 (0.99, 1.07); Q1 (ref) vs Q4: 1.07 (1.03, 1.11); Q1 (ref) vs Q5: 1.11 (1.06, 1.16); P-trend: <0.0001; n-6/n-3 PUFA ratio:; Q1 (ref) vs Q2, Q3, Q4, and Q5: All NS; P-trend: 0.63 | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity, SES (education, income), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: BMI, marital status, history of hypertension, history of hypercholesterolemia, perceived health condition, history of heart disease, stroke, or diabetes mellitus, multi-vitamin use, aspirin use, hormones use (women), energy from protein, other FAs as applicable.; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; National Key Research and Development Program; National Natural Science Foundation of China; China National Program for Support of Top-notch Young Professionals; Intramural Research Program of the NIH, NCI
Hisamatsu, 2013 (https://www.ncbi.nlm.nih.gov/pubmed/23666393) ^166^; PCS, NIPPON, Japan; Baseline N=4,639 Analytic N=4,348 (Attrition: 6%); Participant characteristics at baseline:; - No CVD; - Age: Mean=49.3y; - Sex (female): 0%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI, Mean~23; Fat intake at baseline, Mean:; - Marine-derived n-3 PUFA (%E): Range 0.23-0.57; - ALA (%E): ~0.64; - SFAs (%E): ~5.65; - MUFA (%E): ~7.46; - PUFAs (%E):~ 5.3; Blood lipids at baseline, Mean:; - TC (mg/dL): ~186; - SBP (mmHg): ~138; - DBP (mmHg): ~83; Summary of findings:; In men without J-point elevation, dietary marine–derived n3FAs intake is not associated with risk of cardiac death. | Exposures (medians):; - Marine-derived n-3 PUFA intake (categorical, %E), Mean (SD); - %E <0.35 (n=2111), 0.23 (0.07); - %E≥0.35 (n=2237), 0.57 (0.22); [underlined: Diet assessment method and timing]:; - 3-d weighed food records of households (National Nutritional Survey of Japan (NNSJ); - Estimated individual family member nutrient intake by dividing household intake data proportionally using average intakes by sex and age groups calculated for NNSJ80; - Administered at baseline by trained staff; Outcomes and assessment methods:; - Assessed during 24y (mean=20.4y, SD=6.1y) of follow-up; - [underlined: Cardiac death] risk assessed yearly via government registration records identifying cause of death; - [underlined: Cardiac death]: 200 cases | Marine-derived n-3 PUFA; [underlined: Cardiac deaths,] HR (95% CI),; High marine-derived n-3 (%E≥0.35), no J-point elevation vs low marine-derived n-3 (%E <0.35), no J-point elevation:; 1.01 (0.74–1.38), P>0.05 | Key confounders [underlined: NOT] accounted for:; SES, race/ethnicity, TEI, physical activity, family history of CVD or diabetes; Key confounders accounted for: Age, sex, smoking, alcohol intake; Additional model adjustments: BMI, medication status, SBP, serum total cholesterol, blood glucose, heart rate, left ventricular hypertrophy on electrocardiography, suspected coronary heart disease on electrocardiography, PUFA, SFA, sodium, and fiber intake; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Japanese Ministry of Health, Labor and Welfare
Nakamura, 2013 (https://keio.pure.elsevier.com/en/publications/fatty-acid-intakes-and-coronary-heart-disease-mortality-in-japan-) ^187^; PCS, NIPPON, Japan; Baseline N=8,384 Analytic N=7,819 (Attrition: 7%); Participant characteristics at baseline:; - No CVD; - Diabetes: ~5%; - Age: Mean~55y; - Sex (female): 58%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI, Mean~23; Fat intake at baseline, Mean (SD):; - SFAs (%E): Men 5.9 (1.4), women 6.5 (1.5); - PUFAs (%E): Men: 5.6 (1.3), women, 6.1 (1.4); - Cholesterol (mg/1000kcal): Men: 183.6 (53.2), Women: 200.6 (59.0); Blood lipids at baseline, Mean:; - TC (mg/dL): ~206; - HDL (mg/dL): ~50; Summary of findings:; SFA intake was significantly positively associated with CHD mortality in women, but not in men after 14y follow-up. Polyunsaturated fat and dietary cholesterol intakes were not associated with CHD mortality in middle-aged men or women. | Exposures:; - SFA intake (quintiles, %E), range; - Q1 1.2-4.7; - Q2 4.7-5.5; - Q3 5.5-6.2; - Q4 6.2-7.0; - Q5 7.0-13.0; - SFA intake (categorical, %E); - SFA intake ≤7%E; - SFA intake >7%E; - PUFA intake (quintiles, %E), Mean (SD); - Q1 (Men 4.9(0.05), women 5.2(0.05)); - Q5 (Men 6.1(0.05), women 6.6(0.05)); - Cholesterol intake (quintiles, mg/1000kcal); - Quintiles NR; [underlined: Diet assessment method and timing]:; - 3-d weighed household food records National Nutritional Survey of Japan (NNSJ) 1990; - Estimated individual family member nutrient intake by dividing household intake data from NNSJ90 proportionally using average intakes by sex and age groups calculated for NNSJ95; - Administered at baseline by trained staff; Outcomes and assessment methods:; - Assessed during mean 13.9y, SD= 2.9 of follow-up; - [underlined: CHD mortality] risk assessed yearly via local government registration records identifying cause of death; - Fatal CHD: 72 cases (men 42, women 30) | [underlined: CHD deaths,] HR (95% CI); Men:; SFA (per 1 quintile increase); NS, P-trend=0.46; SFA (categorical, >7%E); SFA >7%E (ref) vs SFA≤7%E: NS, P-trend=0.712; PUFA (per 1 quintile increase); NS, P-trend=0.64; Dietary cholesterol (per 1 quintile increase); NS, P-trend=0.511; Women:; SFA (per 1 quintile increase); 1.34, 95% CI 1.02-1.74, P-trend=0.034; SFA (categorical, >7%E); SFA >7%E (ref) vs SFA≤7%E: 2.59, 95% CI 1.19, 5.63, P=0.016; PUFA (per 1 quintile increase); NS, P-trend=0.974; Dietary cholesterol (per 1 quintile increase); NS, P-trend=0.544 | Key confounders [underlined: NOT] accounted for:; SES, race/ethnicity, TEI, physical activity, family history of CVD or diabetes; Key confounders accounted for: Age, sex, smoking, alcohol intake; Additional model adjustments: BMI, hypertension, diabetes, and dietary intake of vegetables, fruits, and fish; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Japanese Ministry of Health, Labor and Welfare
Miyagawa, 2014 (https://pubmed.ncbi.nlm.nih.gov/26813890-dietary-linolenic-acid-marine-3-fatty-acids-and-mortality-in-a-population-with-high-fish-consumption-findings-from-the-prevencion-con-dieta-mediterranea-predimed-study/?from_term=Dietary+%CE%B1-linolenic+acid%2C+marine+%CF%89-3+fatty+acids%2C+and+mortality+in+a+population+with+high+fish+consumption%3A+Findings+&from_pos=1&from_exact_term=Dietary%5BTitle%5D+AND+alpha-linolenic%5BTitle%5D+AND+acid%5BTitle%5D+AND+marine%5BTitle%5D+AND+omega-3%5BTitle%5D+AND+fatty%5BTitle%5D+AND+acids%5BTitle%5D+AND+mortality%5BTitle%5D+AND+population%5BTitle%5D+AND+high%5BTitle%5D+AND+fish%5BTitle%5D+AND+consumption%5BTitle%5D+AND+Findings%5BTitle%5D) ^185^; PCS, NIPPON, Japan; Baseline N=10,546 Analytic N=9,190 (Attrition: 13%); Participant characteristics at baseline:; - No CVD; - Age: Mean=50.2y; - Sex (female): 56.2%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI, Mean~22.7; Fat intake at baseline, Mean:; - Long chain n-3 PUFA (%E): 0.37; - SFAs (%E): ~5.9; - PUFAs (%E):~ 4.3; - Total n-3 PUFA (%E): ~1.1; Blood lipids at baseline, Mean:; - TC (mg/dL): ~189; Summary of findings:; In men and women, long chain n-3 polyunsaturated fat intake was inversely associated with risk of total CVD, however, no significant association was found with CHD death or fatal stroke during 24y of follow-up. Analysis stratified by age group at baseline found long chain n-3 polyunsaturated fat intake in subjects 30 to 59y inversely associated with CVD death and stroke death during 24y follow-up and no association was found with CHD deaths or in subjects greater than 60y. | Exposures (medians):; - Long chain n-3-PUFA intake (quartiles, g/d, Mean (SD)); - Q1 0.42 (0.15); - Q2 0.74 (0.17); - Q3 1.06 (0.25); - Q4 1.72 (0.62); - DHA (quartiles, %E); - Q1 (Men, 0.00-0.15, Women, 0.01-0.16); - Q2 (Men, 0.16-0.22, Women, 0.17-0.23); - Q3 (Men, 0.23-0.31, Women, 0.24-0.34); - Q4 (Men, 0.32-1.39, Women, 0.35-1.45); [underlined: Diet assessment method and timing]:; - 3-d weighed food records (National Nutritional Survey of Japan); - Administered at baseline by trained staff; Outcomes and assessment methods:; - Assessed during 24y of follow-up; - [underlined: CVD mortality] risk assessed yearly via local government registration records identifying cause of death; - Fatal CVD: 879 cases; - Fatal CHD: 171 cases; - Fatal stroke: 417 cases | Long chain n-3 PUFA; [underlined: CVD deaths,] HR (95% CI),; All:; Q1 (ref) vs Q2: 0.85 (0.70, 1.03); Q1 (ref) vs Q3: 0.85 (0.70,1.03); Q1 (ref) vs Q4: 0.80 (0.66, 0.96); P for trend 0.038; Age 30-59y:; Q1 (ref) vs Q2: 0.92 (0.64,1.32); Q1 (ref) vs Q3: 0.75 (0.51,1.09); Q1 (ref) vs Q4: 0.68 (0.46, 1.00); P for trend 0.031; Age >60y: Q1 (ref) vs Q2, Q3 or Q4: All NS; P-trend=0.323; [underlined: CHD deaths,] HR (95% CI); All, Age 30-59y, and Age >60y:; Q1 (ref) vs Q2, Q3 or Q4: All NS; P-trend: All >0.34; [underlined: Stroke deaths,] HR (95% CI); All: Q1 (ref) vs Q2, Q3 or Q4: All NS; P-trend=0.1115; Age 30-59y:; Q1 (ref) vs Q2: 1.10 (0.64, 1.87); Q1 (ref) vs Q3: 0.95 (0.55, 1.64); Q1 (ref) vs Q4: 0.59 (0.33, 1.08); P for trend 0.043; Age >60y: Q1 (ref) vs Q2, Q3 or Q4: All NS; P-trend=0.497; DHA; [underlined: CVD deaths], HR (95% CI); Q1 (ref) vs Q2: 0.87 (0.72-1.05); Q1 (ref) vs Q3: 0.84 (0.69-1.01); Q1 (ref) vs Q4: 0.79 (0.65-0.96); P for trend 0.023; [underlined: CHD deaths,] HR (95% CI); Q1 (ref) vs Q2, Q3 or Q4: All NS; P-trend=0.261; [underlined: Stroke deaths], HR (95% CI); Q1 (ref) vs Q2, Q3 or Q4: All NS; P-trend=0.121; Analysis stratified by gender and analysis by total n-3FA, and DHA were all NS. See Miyagawa, 2013 for details. | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, TEI, physical activity, family history of CVD or diabetes; Key confounders accounted for: Age, sex, SES (residential area), smoking, alcohol intake; Additional model adjustments: BMI, antihypertensive medication, SBP, total cholesterol, blood glucose, and dietary factors including SFA, PUFA, vegetable protein, fiber, and sodium Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Japanese Ministry of Health, Labor and Welfare
Goldbohm, 2011 (https://pubmed.ncbi.nlm.nih.gov/21270377) ^162^; PCS, NLCS (Netherlands Cohort Study), Netherlands; Baseline N=120,852 Analytic N=20,782 (Attrition: 83%); Participant characteristics at baseline:; - 100% without prevalent CVD; - Age: 55-59y ~37%,60-64y ~34%,65-69y ~29%; - Sex (female): ~38%; - Race/ethnicity: NR; - SES: Education: Primary ~28%, Extended primary ~22%, Secondary (including vocational) ~36%, College/university ~14%; - Anthropometry: BMI ≤22 ~24%, 23-24 ~30%, 25-26 ~24%, ≥27 ~22%; Fat intake at baseline, Mean:; - Butter: Men ~9 g/d, Women ~8 g/d; Blood lipids and BP at baseline: NR; Summary of findings:; Butter was significantly associated with higher incidence of CHD in women only. Butter was not associated with incidence of stroke for men and women. | Exposures:; - Butter (categorical; continuous per 10 g/d); - Category 1 (ref): 0 g/d; - Category 2: Men 25 g/d; Women 20 g/d; [underlined: Assessment method and timing]:; - Validated, semi-quantitative 150-item FFQ to assess usual food intake in previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during mean of 10 y of follow-up; - [underlined: Incident ischemic heart disease (IHD; fatal & nonfatal), stroke:] Dutch Central Bureau of Genealogy and the Dutch Central Bureau of Statistics; - [underlined: IHD:] 2689 cases; - [underlined: Stroke:] 842 cases | [underlined: Incident CHD,] HR (95% CI); [underlined: Butter]; Men:; C1 (ref) vs C2: NS; Continuous per 10 g/d): NS; Women:; C1 (ref) vs C2: NS; Continuous per 10 g/d: 1.13 (1.02, 1.25); [underlined: Incident stroke,] HR (95% CI); [underlined: Butter]; Men:; C1 (ref) vs C2: NS; Continuous per 10 g/d: NS; Women:; C1 (ref) vs C2: NS; Continuous per 10g/d: NS | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, SES (education), TEI, alcohol intake, physical activity, smoking; Additional model adjustments: BMI, multivitamin use, energy-adjusted MUFA and PUFA, vegetable and fruit consumption; Limitations:; - Not all key confounders adjusted for; - Potential bais in classification of exposures due to butter as a proxy for types of fats; - Potential missing data bias due to unknown attrition from missing data; - No preregistered statistical analyis plan; Funding sources:; Dutch Dairy Foundation
Gardener, 2011 (https://pubmed.ncbi.nlm.nih.gov/22071704/) ^161^; PCS, NOMAS (Northern Manhattan Study), U.S.; Baseline N=3,298 Analytic N=2,568 (Attrition: 22%); Participant characteristics at baseline:; - 100% without MI and never diagnosed with Ischemic stroke; - Age: Mean: 69 y (SD=10); - Sex (female): 64%; - Race/ethnicity: Hispanic 55%, Black 24%, White 21%; - SES: High school completion: Yes 45%, No 55%; - Anthropometry: NR; Fat intake at baseline, Mean (SD):; - MUFA:SFA: 1.20 g/d (0.34); Blood lipids and BP at baseline: NR; Summary of findings:; MUFA:SFA ratio was not significantly associated with vascular deaths. | Exposures:; - MUFA:SFA (continuous, g/d); [underlined: Assessment method and timing]:; - Interview-administered, validated FFQ (Block National Cancer Institute) to assess usual intake in the previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 9 y of follow-up; - [underlined: Vascular deaths:] follow-up, medical records; - [underlined: Vascular events:] 518 cases; - Ischemic strokes: 171; - MI: 133; - Vascular deaths: 314 | [underlined: Vascular deaths,] HR (95% CI); [underlined: MUFA:SFA:] NS | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes; Key confounders accounted for: Sex, age, race/ethnicity, SES (educational level), TEI excluding alcohol, alcohol intake, physical activity, smoking; Additional model adjustments: All Mediterranean-style diet score components (alcohol, fish, legumes, vegetables, fruit, cereal, meat, dairy); Limitations:; - Not all key confounders accounted for; - Analyses did not account for co-exposures (PUFA); - Risk of missing data bias due to relatively high attrition; - No preregistered statistical analysis plan; Funding sources:; National Institute of Neurological Disorders and Stroke
Wilk, 2012 (https://pubmed.ncbi.nlm.nih.gov/22952185) ^219^; PCS, PHS (Physicians’ Health Study), U.S.; Baseline N=19,649 Analytic N=19,097 (Attrition: 3%); Participant characteristics at baseline:; - 100% male physicians; - Age: ~66 y; - Sex (female): 0%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI ~26; Fat intake at baseline, Mean (SD):; See “Results”; Blood lipids and BP at baseline:; - Hypertension: 43%; - High cholesterol: 42%; Summary of findings:; Marine n-3 FAs and ALA were not associated with incidence of heart failure in male physicians. | Exposures:; - Marine n-3 FAs (EPA+DHA+DPA) (quintiles), Median; - Q1: 0.079 g/d; - Q3: 0.152 g/d; - Q5: 0.397 g/d; - ALA (quintiles), Median; - Q1: 0.576 g/d; - Q3: 0.765 g/d; - Q5: 1.0 g/d; [underlined: Assessment method and timing]:; - Validated FFQs; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 13 y of follow-up; - [underlined: Heart failure:] follow-up questionnaires, self-reported diagnosis, medical records; - [underlined: Heart failure:] 703 cases | [underlined: Heart failure,] HR (95% CI); [underlined: Marine n-3 FAs:]; Q1 vs Q2, Q3, Q4, Q5: All NS; P linear trend=NS; [underlined: ALA:]; Q1 vs Q2, Q3, Q4, Q5: All NS; P linear trend=NS | Key confounders [underlined: NOT] accounted for:; Sex, age, race/ethnicity, SES (educational level), TEI, family history of CVD or diabetes; Key confounders accounted for: Alcohol intake, physical activity, smoking; Additional model adjustments: Atrial fibrillation, valvular heart disease, hypertension, BMI; Limitations:; - Not all key confounders accounted for; - Analyses did not account for co-exposures (other types of fats); - No preregistered statistical analysis plan; Funding sources:; NHLBI; Office of Dietary Supplements, NIH; National Cancer Institute, National Heart, Lung, and Blood Institute
Guasch-Ferré, 2014 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4030221/) ^164^; PCS, PREDIMED, Spain; Baseline N=7,447 Analytic N=7,216 (Attrition: 3%); Participant characteristics at baseline:; - High CVD risk, but no CVD; - Type 2 diabetes: ~49%; - Age: Mean=67y; - Sex (female): 57.4%; - Race/ethnicity: NR; - SES: Education: 78% Illiterate/primary, 15% Secondary, 7% Academic/graduate; - Anthropometry: BMI, Mean~30.0; Fat intake at baseline: See olive oil intake under exposures; Blood lipids and BP at baseline:; - Hypercholesterolemia: ~72%; - Hypertension: ~83%; Summary of findings:; Higher Baseline total olive oil consumption, was associated with a significant reduced risk of major cardiovascular events and cardiovascular mortality in an elderly Mediterranean population at high cardiovascular risk. | Exposures:; - Olive oil intake at baseline (tertiles, energy-adjusted,g/d); - T1 (ref; mean: 21.4, SD=8.00); - T2 (mean 38.8, SD=11.6); - T3 (mean 56.9, SD=10.8); - Olive oil intake (energy adjusted continuous, per 10g/day); [underlined: Diet assessment method and timing]:; - Validated 137-item semi-quantitative FFQ (3 questions related to olive oil); during face-to-face interviews, participants were asked about frequency of consumption and specific varieties; - Administered at baseline and during yearly follow-ups; Outcomes and assessment methods:; - Assessed during median 4.8y of follow-up; - [underlined: Major CVD events and mortality] ascertained by yearly questionnaires and exams, primary care physicians, medical records and linkage to the National Death Index; - [underlined: Major cardiovascular event] (composite of myocardial infarction, stroke and death from cardiovascular causes): 277 cases; - [underlined: Cardiovascular deaths]: 81 cases | [underlined: Major cardiovascular event], HR (95% CI); Olive oil intake (tertiles); T1 (ref) vs T2: 0.78 (0.58, 1.04); T1 (ref) vs T3: 0.65 (0.47, 0.89),; P for trend 0.01; Total olive oil intake (continuous); 0.87 (0.81, 0.94); [underlined: Cardiovascular deaths,] HR (95% CI); Olive oil intake (tertiles); T1 (ref) vs T2: 0.69 (0.40, 1.18); T1 (ref) vs T3: 0.52 (0.29, 0.93); P for trend 0.04; Olive oil intake (continuous); 0.84 (0.73, 0.96) | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Age, sex, SES (education), TEI, smoking, alcohol intake, physical activity; Additional model adjustments: Intervention group, BMI, prevalence of diabetes, hypertension and hypercholesterolemia, use of hypertensive medication, use of statins, baseline Mediterranean diet adherence; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Spanish Ministry of Health, Centre Català de la Nutrició de l’Institut d’Estudis Catalans, the Fundación Patrimonio Comunal Olivarero and Hojiblanca SA, California Walnut Commission, Borges SA, and Morella Nuts
Guasch-Ferré, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/26561617) ^163^; PCS, PREDIMED, Spain; Baseline N=7,447 Analytic N=7,038 (Attrition: 4%); Participant characteristics at baseline:; - High CVD risk, but no CVD; - Type 2 diabetes: ~49%; - Age: Mean=67y, SD=6; - Sex (female): 57.4%; - Race/ethnicity: NR; - SES: Education: 78% Illiterate/primary, 19% Secondary, 4% Academic/graduate; - Anthropometry: BMI, Mean~30.0; Fat intake at baseline, Mean (SD):; - SFA (%E): 9.9 (2.2); - MUFA (%E): 19.6 (4.5); - PUFA (%E): 6.2 (2.0); - Trans FA (%E): 0.22 (0.14); - Dietary Cholesterol (mg/d): 361.3 (123.3); - Total fat (%E): 39.3 (6.8); Blood lipids and BP at baseline:; - Hypercholesterolemia: ~72%; - Hypertension: ~83%; Summary of findings:; Higher intakes of MUFAs and PUFAs were significantly associated with a lower risk of CVD and higher intakes of SFA from pastries and processed foods were significantly associated with a higher risk of CVD in an elderly Mediterranean population with high risk of CVD. | Exposures:; - SFA (quintiles; %E); - Q1 (ref; mean=7.0, SD=0.8); - Q5 (mean=13.2, SD=1.4); - MUFA (quintiles; %E); - Q1 (ref; mean: 13.4, SD=1.8); - Q5 (mean=26.1, SD=2.4); - PUFA (quintiles; %E); - Q1 (ref; mean: 4.0, SD=0.47); - Q5 (mean 9.4, SD=1.8); - Isocaloric replacement of SFA with CHO, MUFA and PUFA (continuous, median intake for each quintile, %E); - SFA intake from different food source; - Vegetable (oils, nuts, vegetables, margarine); - Dairy; - Pastry and other processed foods (cookies, donuts, bakery, sauces, pizza, other); - Meat and processed-meat (sausages, hamburger, other, and eggs); - Fish/seafood; [underlined: Diet assessment method and timing]:; - Validated 137-item semi-quantitative FFQ (3 questions related to olive oil); during face-to-face interviews, participants were asked about frequency of consumption and portion; - Administered at baseline and during yearly follow-ups; Outcomes and assessment methods:; - Assessed during median 6y of follow-up; - [underlined: Major CVD events and mortality] ascertained by yearly questionnaires and exams, primary care physicians, medical records and linkage to the National Death Index; - [underlined: Major cardiovascular event] (composite of myocardial infarction, stroke and death from cardiovascular causes): 336 cases; - [underlined: Cardiovascular deaths]: 102 cases; Exposures:; - SFA (quintiles; %E); - Q1 (ref; mean=7.0, SD=0.8); - Q5 (mean=13.2, SD=1.4); - PUFA (quintiles; %E); - Q1 (ref; mean: 4.0, SD=0.47); - Q5 (mean 9.4, SD=1.8); - MUFA (quintiles; %E); - Q1 (ref; mean: 13.4, SD=1.8); - Q5 (mean=26.1, SD=2.4); - Isocaloric replacement of SFA with CHO, MUFA and PUFA (continuous, median intake for each quintile, %E); - SFA intake from different food source; - Vegetable (oils, nuts, vegetables, margarine); - Dairy; - Pastry and other processed foods (cookies, donuts, bakery, sauces, pizza, other); - Meat and processed-meat (sausages, hamburger, other, and eggs); - Fish/seafood | [underlined: Major cardiovascular event], HR (95% CI); SFA; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.07; MUFA; Q1 (ref) vs Q2: 0.88 (0.61, 1.26); Q1 (ref) vs Q3: 0.66 (0.44, 0.98); Q1 (ref) vs Q4: 0.76 (0.50, 1.16); Q1 (ref) vs Q5: 0.50 (0.31, 0.81); P for trend< 0.01; PUFA; Q1 (ref) vs Q2: 0.78 (0.56, 1.09); Q1 (ref) vs Q3: 0.72 (0.51, 1.02); Q1 (ref) vs Q4: 0.71 (0.51, 1.01); Q1 (ref) vs Q5: 0.68 (0.48, 0.96); P for trend= 0.04; [underlined: Cardiovascular deaths,] HR (95% CI); PUFA; Q1 (ref) vs Q5: 0.37 (0.18, 0.76); P for trend <0.01; MUFA; Q1 (ref) vs Q5: 0.78 (0.34, 0.97); P for trend <0.01; SFA; Q1 (ref) vs Q5: NS; P-trend=NR; SFA sources; [underlined: Major cardiovascular event], HR (95% CI); Vegetable SFA; Q1 (ref) vs Q2, Q3, or Q4: All NS; Q1 vs Q5: 0.53 (0.30, 0.93); P-trend=0.06; Dairy SFA; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.54; Pastry and other processed foods SFA; Q1 (ref) vs Q2: 1.21 (0.83, 1.78); Q1 (ref) vs Q3: 1.09 (0.74, 1.63); Q1 (ref) vs Q4: 1.44 (0.99, 2.09); Q1 (ref) vs Q5: 1.46 (1.01, 2.13); P for trend= 0.04; Meat, processed-meat and eggs SFA; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend=0.28; Fish/seafood SFA; Q1 (ref) vs Q2, Q3, or Q4: All NS; Q1 vs Q5: 0.70 (0.46, 0.99); P-trend=0.11; Replacement; [underlined: Major cardiovascular event], HR (95% CI); Replacement of CHO (per 5%):; With MUFA: 0.79 (0.68, 0.92), P<0.05; With PUFA: 0.78 (0.59, 0.97), P<0.05; With SFA: 1.35 (1.03, 1.77), P<0.05; Replacement of SFA (per 5%E):; With MUFA: 0.63 (0.43, 0.94), P<0.05; With PUFA: 0.67 (0.45, 0.98), P<0.05 | Key confounders [underlined: NOT] accounted for: Race/ethnicity; Key confounders accounted for: Age, sex, SES (education), TEI, smoking, alcohol intake, physical activity, family history of CVD; Additional model adjustments: Intervention group, BMI, baseline diabetes, hypertension and hypercholesterolemia, use of hypertensive medication, use of oral antidiabetic agents, use of lipidlowering drugs, updated quintiles of fiber, protein, and dietary cholesterol and other subtypes of fat; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources: Spanish Ministry of Health, Centre Català de la Nutrició de l’Institut d’Estudis Catalans, Instituto de Salud Carlos III, Centro Nacional de Investigaciones Cardiovasculares, Fondo de Investigación Sanitaria–Fondo Europeo de Desarrollo Regional, Ministerio de Ciencia e Innovación, Fundación Mapfre 2010, Consejería de Salud de la Junta de Andalucía, Public Health Division of the Dept of Health of the Autonomous Govt of Catalonia, Generalitat Valenciana, the Regional, Government of Navarra, Fundación Patrimonio Comunal Olivarero and Hojiblanca SA, California Walnut Commission, Borges SA, and Morella Nuts SA, CIBEROBN (Centro de Investigación Biomédica en Red de Fisiopatología de la Obesidad y Nutrición) and CIBERDEM -.
Sala-Vila, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/26813890) ^202^; PCS, PREDIMED, Spain; Baseline N=7,447 Analytic N=7202 (Attrition: 3%); Participant characteristics at baseline:; - High CVD risk, but no CVD; - Type 2 diabetes: 48.8%; - Age: Mean=67y; - Sex (female): 57.1%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI, Mean=30.0; Fat intake at baseline, Mean:; - SFAs (g/d): 24.8; - MUFAs (g/d): 48.2; - PUFAs (g/d): 13.0; - ALA (g/d): 1.40; - ALA (%E): 0.06; - Cholesterol (mg/d): 361; Blood lipids and BP at baseline:; - Dyslipidemia: 72.2%; - Hypertension: 82.7%; Summary of findings:; In a high cardiovascular risk population, long chain n-3 polyunsaturated fat intake greater than 500mg/day had a protective effect on CVD and CHD mortality, but not on sudden cardiac death or fatal stroke. ALA intake greater than 0.7 percent energy per day had no effect on CVD and CHD mortality related outcomes. | Exposures:; - ALA intake (categorical, %E); - ALA intake ≥0.7%E; - ALA intake <0.7%E; - Long chain (LC) n-3-PUFA intake (categorical, mg/d); - LCn-3 ≥500mg/d; - LCn-3 <500mg/d; [underlined: Diet assessment method and timing]:; - Validated 137-item semi-quantitative FFQ (8 items on seafood and 6 items regarding major ALA sources); during face-to-face interviews, participants were asked about frequency of consumption and portion; - Administered at baseline and during yearly follow-ups.; Outcomes and assessment methods:; - Assessed during ~5.9y of follow-up; - [underlined: CVD and CHD mortality] assessed yearly via contact with physicians and yearly review of medical records and linkage with the National Death Index; - [underlined: Fatal CVD]: 104 cases; - [underlined: Fatal CHD]: 55 cases; - [underlined: Sudden cardiac death]: 32 cases; - [underlined: Fatal stroke]: 25 cases | ALA; [underlined: Fatal CVD], HR (95% CI); ALA intake <0.7%E (Ref) vs ALA intake ≥0.7%E: P>0.05; [underlined: Fatal CHD,] HR (95% CI); ALA intake <0.7%E (Ref) vs ALA intake ≥0.7%E: P>0.05; [underlined: Sudden cardiac death,] HR (95% CI); ALA intake <0.7%E (Ref) vs ALA intake ≥0.7%E: P>0.05; [underlined: Fatal stroke,] HR (95% CI); ALA intake <0.7%E (Ref) vs ALA intake ≥0.7%E: P>0.05; LCn-3PUFA; [underlined: Fatal CVD,] HR (95% CI); LCn-3PUFA intake <500mg/d (Ref) vs LCn-3PUFA intake ≥500mg/d:; 0.614 (0.393–0.960), P=0.032; [underlined: Fatal CHD,] HR (95% CI); LCn-3PUFA intake <500mg/d (Ref) vs LCn-3PUFA intake ≥500mg/d:; 0.537 (0.292–0.988), P=0.046; [underlined: Sudden cardiac death,] HR (95% CI); LCn-3PUFA intake <500mg/d (Ref) vs LCn-3PUFA intake >500mg/d: P>0.05; [underlined: Fatal stroke,] HR (95% CI); LCn-3PUFA intake <500mg/d (Ref) vs LCn-3PUFA intake ≥500mg/d: P>0.05 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, SES; Key confounders accounted for: Age, sex, TEI, smoking, alcohol intake, physical activity, family history of CVD or diabetes; Additional model adjustments: Intervention group, BMI, history of diabetes, history of hyperlipidemia, history of hypertension, and dietary factors (fiber, vegetables, fruits, and red meat); Limitations:; - Not all key confounders accounted for; - Analyses did not account for co-exposures (e.g. SFA, PUFA, MUFA); - No preregistered statistical analysis plan; Funding sources:; Instituto de Salud Carlos III (Spanish Ministry of Economy), Spanish Ministry of Science and Innovation, California Walnut Commission, Spanish Ministry of Economy and Competitiveness
Praagman, 2016a (https://www.ncbi.nlm.nih.gov/pubmed/27417581) ^197^; PCS, Rotterdam Study, Netherlands; Baseline N=7,983, Analytic N=4,722 (Attrition: 40%); Participant characteristics at baseline:; - Noninstitutionalized men and women 55y or older without prevalent CVD; - Age: Mean~67y; - Sex (female): 62%; - Race/ethnicity: NR; - SES: High education level, ~9%; - Anthropometry: BMI, Mean~26.3; Fat intake at baseline:; - Total SFA (quintiles; %E), Mean (SD); - Q1: 11.2 (1.4); - Q2: 13.9 (0.5); - Q3: 15.6 (0.5); - Q4: 17.5 (0.6); - Q5: 20.8 (1.9); Blood lipids and BP at baseline:; - HDL (mmol/L): Mean=1.4, SD=0.4; - Hypertension: 53%; Summary of findings:; In men and women, intake of total SFA and SFA from different sources at ~67y of age was not significantly associated with incident CHD during ~16.3y of follow-up. Replacement of SFA with animal protein, but not other macronutrients, was significantly associated with higher risk of incident CHD. | Exposures:; - Total SFA (continuous; per 5%E); - SFA from sources:; - Butter (among consumers only, n=1551; continuous; per 2.8%E); - Cheese (continuous; per 1.9%E); - Milk (continuous; per 1.5%E); - Meat (continuous; per 1.5%E); - Cakes (continuous; per 1.5%E); - Hard and solid fats (continuous; per 1.5%E); - Soft and liquid fats (continuous; per 1.5%E); - Other sources (continuous; per 1.5%E); - Replacement of SFA with:; - CHO (continuous; per 5%E); - Low-GI CHO (continuous; per 5%E); - Medium-GI CHO (continuous; per 5%E); - High-GI CHO (continuous; per 5%E); - Cis-MUFA (continuous; per 5%E); - PUFA (continuous; per 5%E); - Protein (continuous; per 5%E); - Animal protein (continuous; per 5%E); - Vegetable protein (continuous; per 5%E); [underlined: Assessment method and timing]:; - Validated, semi-quantitative, 170-item FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~16.3y of follow-up; - [underlined: Incident CHD:] Obtained through linkage with digital municipality records and digital files from general practitioners; Incident CHD included fatal and nonfatal MI, and definite coronary mortality; - [underlined: Total:] 659 cases | [underlined: Incident CHD,] HR (95% CI); Total SFA: 1.13 (0.94, 1.36); Sources:; Butter: 1.08 (0.88, 1.31); Cheese: 1.03 (0.94, 1.13); Milk: 1.04 (0.94, 1.14); Meat: 1.09 (0.99, 1.20); Cakes: 1.02 (0.92, 1.13); Hard and solid fats: 1.05 (0.92, 1.19); Soft and liquid fats: 1.07 (0.97, 1.18); Other sources: 1.05 (0.96, 1.15); Replacement of SFA with:; CHO: 0.90 (0.80, 1.02); Low-GI CHO: 0.96 (0.78, 1.19); Medium-GI CHO: 0.84 (0.68, 1.05); High-GI CHO: 0.94 (0.77, 1.14); cis-MUFA: 1.09 (0.98, 1.22); PUFA: 0.90 (0.71, 1.15); Protein: 1.22 (1.00, 1.49); Animal Protein: 1.24 (1.01, 1.51); Vegetable Protein: 0.88 (0.50, 1.53) | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity, SES (education, income), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: BMI, WC, intake of trans-fat, vegetable protein, animal protein, cholesterol, fiber, and vitamin C; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of institutionalized participants; - No preregistered statistical analysis plan; Funding sources:; Erasmus MC University Medical Centre; Erasmus University Rotterdam; The Netherlands Organization for Scientific Research; The Netherlands Organization for Health Research and Development; Research Institute for Diseases in the Elderly; The Netherlands Genomics Initiative; The Netherlands Consortium of Healthy Ageing; Ministry of Education, Culture and Science; Ministry of Health, Welfare and Sports; European Commission (DG XII); Municipality of Rotterdam
Kiage, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/26298428) ^173^; PCS, SCCS (Southern Community Cohort Study), U.S.; Baseline N>85,000 (did not provide exact number), Analytic N=69,559 (Attrition: ~18% or higher); Participant characteristics at baseline:; - Men and women 40-79y of age from the southern U.S. at baseline; - Age: Mean=52y, SD=9y; - Sex (female): ~60%; - Race/ethnicity: ~32% White; - SES: Education, 28% <High School, 39% High school/GED, 20% Some college, 13% Graduate; Income <$15,000/y, 55%; - Anthropometry: BMI, Mean=30, SD=8; Fat intake at baseline:; - Total PUFA (quintiles; energy adjusted intake), Mean (SD); - Q1: 12.2 (2.5) g/d; 6.1 (1.6) %E; - Q2: 17.0 (0.9) g/d; 7.2 (1.2) %E; - Q3: 19.8 (0.8) g/d; 7.9 (1.0) %E; - Q4: 22.6 (0.9) g/d; 8.6 (0.9) %E; - Q5: 27.1 (2.8) g/d; 10.1 (1.2) %E; BP at baseline:; - Hypertension: 54%; Summary of findings:; In men and women not on statins, n-6 PUFA intake, but not n-3 PUFA intake, at ~52y of age was significantly associated with lower risk of CVD mortality during ~6.4y of follow-up. In men and women using statins, n-3 and n-6 PUFA intake was not significantly associated with CVD mortality. | Exposures:; - n-3 PUFA (quintiles; energy adjusted intake); - n-6 PUFA (quintiles; energy adjusted intake); [underlined: Assessment method and timing]:; - Validated, 89-item FFQ; assistance from trained staff with 86% of participants; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~6.4y of follow-up; - [underlined: CVD Mortality:] Obtained through linkage with Social Security Administration and the National Death Index; - [underlined: Total CVD:] 2023 cases | n-3 PUFA; [underlined: CVD Mortality,] HR (95% CI); Statin users (~16%); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.35; Non-users (~84%); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.57; n-6 PUFA; [underlined: CVD Mortality,] HR (95% CI); Statin users (~16%); Q1 (ref) vs Q2: 0.65 (0.48, 0.89); Q1 (ref) vs Q3: 0.88 (0.65, 1.19); Q1 (ref) vs Q4: 0.77 (0.56, 1.07); Q1 (ref) vs Q5: 0.80 (0.57, 1.12); P-trend: 0.48; Non-users (~84%); Q1 (ref) vs Q2: 0.83 (0.70, 0.98); Q1 (ref) vs Q3: 0.74 (0.61, 0.90); Q1 (ref) vs Q4: 0.80 (0.65, 0.98); Q1 (ref) vs Q5: 0.72 (0.57, 0.93); P-trend: 0.03 | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes.; Key confounders accounted for: Sex, age, race/ethnicity, SES (education, income), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: BMI, recruitment site, energy adjusted SFA, MUFA, and protein, diabetes, statin use, statin use by n-3 or n-6 PUFA interaction; Limitations:; - Not all key confounders accounted for; - No information on selection of participants into analysis; - No information on missing data; - No preregistered statistical analysis plan; Funding sources:; National Cancer Institute; American Recovery and Reinvestment Act; PepsiCo Global Research and Development
Koh, 2015 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4501020/) ^175^; PCS, SCHS (Singapore Chinese Health Study), Singapore; Baseline N=63,287 Analytic N=60,298 (Attrition: 5%); Participant characteristics at baseline:; - No CVD or cancer; - Age: Mean~56y; - Sex (female):~58%; - Race/ethnicity: NR; - SES: Education: ~28% more than secondary school; - Anthropometry: BMI, Mean~23; Fat intake at baseline:; - See exposure section; Blood lipids and BP at baseline: NR; Summary of findings:; Higher intakes of EPA/DHA and ALA omega-3 fatty acids were associated with reduced risk of cardiovascular mortality, and coronary heart disease mortality, but not stroke mortality in a Chinese population. | Exposures (medians):; - Total n-3 PUFA (quartiles, g), Mean, SD; - Q1 0.59, 0.12; - Q2 0.79, 0.04; - Q3 0.92, 0.04; - Q4 1.26, 0.33; - EPA+DHA intake (quartiles, g) Mean, SD (by quartile of total n-3 PUFA intake); - Q1 0.19, 0.10; - Q2 0.28, 0.09; - Q3 0.35, 0.10; - Q4 0.46, 0.18; - ALA intake (quartiles, g) Mean, SD (by quartile of total n-3 PUFA intake); - Q1 0.40, 0.11; - Q2 0.51, 0.09; - Q3 0.56, 0.10; - Q4 0.80, 0.36; [underlined: Diet assessment method and timing]:; - 165-item semi-quantitative FFQ (validated) with 14 seafood items; - Administered at baseline; Outcomes and assessment methods:; - Assessed during ~15 years of follow-up; - [underlined: CVD death] assessed via linkage to birth and death registry of Singapore; - [underlined: CVD death]: 4780 cases; - [underlined: CHD death]: 2697 cases; - [underlined: Stroke death]: 1298 cases | [underlined: CVD deaths,] HR (95% CI),; Total n-3 PUFA; Q1 (ref) vs Q2: 0.88 (0.81, 0.96); Q1 (ref) vs Q3: 0.88 (0.80, 0.97); Q1 (ref) vs Q4: 0.83 (0.74, 0.92); P-trend 0.003; EPA+DHA; Q1 (ref) vs Q2: 0.96 (0.89, 1.05); Q1 (ref) vs Q3: 0.90 (0.82, 0.99); Q1 (ref) vs Q4: 0.86 (0.77, 0.96); P-trend 0.004; ALA; Q1 (ref) vs Q2: 0.94 (0.86, 1.02); Q1 (ref) vs Q3: 0.87 (0.79, 0.95); Q1 (ref) vs Q4: 0.81 (0.73, 0.90); P-trend ≤0.001; [underlined: CHD deaths,] HR (95% CI); Total n-3 PUFA; Q1 (ref) vs Q2: 0.92 (0.81, 1.03); Q1 (ref) vs Q3: 0.92 (0.80, 1.03); Q1 (ref) vs Q4: 0.85 (0.73, 0.98); P-trend 0.04; EPA+DHA; Q1 (ref) vs Q2 0.99 (0.88, 1.10); Q1 (ref) vs Q3: 0.97 (0.85, 1.09); Q1 (ref) vs Q4: 0.86 (0.74, 0.99); P-trend 0.02; ALA; Q1 (ref) vs Q2: 1.01 (0.90–1.13); Q1 (ref) vs Q3: 0.90 (0.79–1.01); Q1 (ref) vs Q4: 0.82 (0.71–0.93); P-trend 0.001; [underlined: Stroke deaths,] HR (95% CI); Total n-3 PUFA; Q1 (ref) vs Q2, Q3 or Q4: NS, P-trend=0.10; EPA+DHA; Q1 (ref) vs Q3: 0.82 (0.68-0.98); Q1 (ref) vs Q2 or Q4: NS, P-trend=0.28; ALA; Q1 (ref) vs Q2: 0.81 (0.68, 0.95); Q1 (ref) vs Q3: 0.81 (0.68, 0.97); Q1 (ref) vs Q4: 0.81 (0.67, 0.99); P-trend=0.07 | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes; Key confounders accounted for: Age, sex, SES (education, residential area), race/ethnicity (dialect group), smoking, alcohol intake, TEI, physical activity; Additional model adjustments: Interview year, BMI, history of comorbidities at baseline (diabetes, hypertension, CHD, and stroke), fiber, protein, and all fat subtypes (i.e. omega-6 fatty acids, monounsaturated fat, and saturated fat); Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; U.S. National Institutes of Health
Neelakantan, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/29982724) ^188^; PCS, SCHS (Singapore Chinese Health Study), Singapore; Baseline N=63,257, Analytic N=57,078 (Attrition: 10%); Participant characteristics at baseline:; - Singapore Chinese men and women 45-74y of age without cancer or CVD at baseline.; - Age: ~56y; - Sex (female): ~56%; - Race/ethnicity: 100% ethnic Chinese; - SES: Higher education ~30%; - Anthropometry: BMI ~23; Fat intake at baseline, Mean:; - SFA: ~9%E; - MUFA:SFA ratio: ~1; - PUFA: ~5%E; - Long-chain n-3 PUFA: ~0.3 g/d; - Cholesterol: ~180 mg/d; Blood lipids and BP at baseline:; - Hypertension: ~21%; Summary of findings:; In men and women, SFA intake of 10-15%E (but not >15%E) compared to 0-10%E at ~56y of age was significantly associated with lower risk of CVD mortality. Higher intake of long chain n-3 PUFA was significantly associated with lower risk of CVD mortality. Intake of PUFA and cholesterol, and the MUFA:SFA intake ratio were not associated with risk of CVD mortality. | Exposures:; - SFA (categorical; %E); - 0-10%E (ref); - 10-15%E; - >15%E; - MUFA:SFA ratio (continuous); - PUFA (categorical; %E); - 0-6%E; - 6-10%E (ref); - >10%E; - Long chain n-3 PUFA (continuous; g/d); - Cholesterol (continuous; per 100 mg/d); [underlined: Assessment method and timing]:; - Validated, semi-quantitative, 165-item FFQ assessing intake during the previous year; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~17y of follow-up; - [underlined: CVD Mortality:] Obtained through linkage with nationwide registry of deaths; - [underlined: Total:] 4871 cases | SFA; [underlined: CVD Mortality,] HR (95% CI); 0-10%E (ref) vs 10-15%E: 0.90 (0.84, 0.97); 0-10%E (ref) vs >15%E: 0.98 (0.72, 1.33); MUFA:SFA ratio; [underlined: CVD Mortality,] HR (95% CI); 1.17 (1.00, 1.36); PUFA; [underlined: CVD Mortality,] HR (95% CI); 6-10%E (ref) vs 0-6%E: 1.00 (0.93, 1.08); 6-10%E (ref) vs >10%E: 1.14 (0.91, 1.43); Long chain n-3 PUFA; [underlined: CVD Mortality,] HR (95% CI); 0.74 (0.58, 0.94); Cholesterol; [underlined: CVD Mortality,] HR (95% CI); 1.04 (1.00, 1.09) | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes; Key confounders accounted for: Sex, age, race/ethnicity, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: Sleep duration, dialect (hokkien or Cantonese), BMI, history of diabetes mellitus, history of hypertension, intake of dietary fiber, long-chain n-3 PUFA, cholesterol, sodium, SFA, mono- and disaccharides, PUFAs, protein.; Limitations:; - Not all key confounders accounted for; - How categories of intake levels were selected for analysis was not reported; - No preregistered statistical analysis plan; Funding sources:; NCI; National Medical Research Council, Singapore
Levitan, 2010 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2880209/) ^182^; PCS, SIMPLER: SMC (Swedish Mammography Cohort), Sweden; Baseline N=39,227, Analytic N=36,234 (Attrition: 8%); Participant characteristics at baseline:; - Women without history of MI, diabetes, or cancer (other than non-melanoma skin cancer) at baseline; - Age: Mean~62y; - Sex (female): 100%; - Race/ethnicity: NR; - SES: Education, ~75% less than high school, ~8% high school, ~17% university; - Anthropometry: BMI, Mean~25; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - History of high cholesterol: ~20%; - History of hypertension: ~8%; Summary of findings:; Among women, marine n-3 PUFA intake at ~62y of age was not significantly associated with incident heart failure during ~9y of follow-up. | Exposures:; - Marine n-3 PUFA intake (quintiles; g/d), Median (range):; - Q1 (ref): 0.14 (0.01-0.19); - Q2: 0.23 (0.20-0.27); - Q3: 0.30 (0.28-0.33); - Q4: 0.38 (0.34-0.45); - Q5: 0.57 (0.46-7.15); [underlined: Assessment method and timing]:; - Self-administered, validated, 96-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~9y of follow-up; - [underlined: Incident heart failure (HF; hospitalization or mortality):] Obtained via linkage with Swedish inpatient and cause-of-death registers; - [underlined: Total:] 651 cases (596 hospitalizations, 55 deaths) | Marine n-3 PUFA; [underlined: Incident HF,] Rate Ratio (95% CI); Q1 (ref) vs Q2: 0.87 (0.69, 1.11); Q1 (ref) vs Q3: 0.83 (0.64, 1.07); Q1 (ref) vs Q4: 0.88 (0.69, 1.12); Q1 (ref) vs Q5: 0.81 (0.63, 1.05); P-trend: NR; Results were similar when a broader definition of HF diagnosis was utilized.; When analyses were restricted to women without self-reported hypertension at baseline, no consistent associations across quintiles were detected. | Key confounders [underlined: NOT] accounted for:; Race/ethnicity.; Key confounders accounted for: Sex, age, SES (education), TEI, smoking, alcohol intake, physical activity, family history of CVD or diabetes.; Additional model adjustments: BMI, living alone, postmenopausal hormone use, fiber intake, sodium intake, intake of red or processed meat, self-reported history of hypertension, self-reported history of high cholesterol, intake of protein, SFA, MUFA, non-marine n-3 FA, and n-6 FA.; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of women with diabetes at baseline; - No preregistered statistical analysis plan; Funding sources:; Swedish Research Council/Committee for Infrastructure and Committee for Medicine; Swedish Foundation for International Cooperation in Research and Higher Education; NHLBI
Larsson, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22265275) ^179^; PCS, SIMPLER: SMC (Swedish Mammography Cohort), Sweden; Baseline N=39,227, Analytic N=34,670 (Attrition: 12%); Participant characteristics at baseline:; - Women 49-83y without history of stroke, coronary heart disease, or cancer at baseline; - Age: Mean~62y; - Sex (female): 100%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: NR; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - NR; Summary of findings:; Among women, higher intake of long chain n-3 PUFAs (EPA+DHA) at ~62y of age was significantly associated with lower risk of stroke, specifically cerebral infarctions, during ~10.4y of follow-up. Higher intake of cholesterol was significantly associated with higher risk of stroke, specifically cerebral infarctions. Intake of SFA, MUFA, ALA, and n-6 PUFAs were not significantly associated with risk of stroke. | Exposures:; - SFA (quintiles; g/d), Median: (Q1 (ref): 19.5; Q2: 23.8; Q3: 26.9; Q4: 30.3; Q5: 35.5); - MUFA (quintiles; g/d), Median: (Q1 (ref): 15.6; Q2: 18.3; Q3: 20.0; Q4: 21.7; Q5: 24.3); - PUFA (quintiles; g/d), Median: (Q1 (ref): 6.1; Q2: 7.1; Q3: 7.8; Q4: 8.6; Q5: 10.1); - ALA (quintiles; g/d), Median: (Q1 (ref): 0.9; Q2: 1.0; Q3: 1.1; Q4: 1.3; Q5: 1.5); - EPA+DHA (quintiles; mg/d), Median: (Q1 (ref): 131; Q2: 222; Q3: 289; Q4: 370; Q5: 559); - EPA+DHA (continuous; per 500 mg/d):; - n-6 PUFA (quintiles; g/d), Median: (Q1 (ref): 4.7; Q2: 5.4; Q3: 6.0; Q4: 6.6; Q5: 8.0); - Cholesterol (quintiles; mg/d), Median: (Q1 (ref): 168; Q2: 204; Q3: 229; Q4: 255; Q5: 302); - Cholesterol (continuous; per 120 mg/d):; [underlined: Assessment method and timing]:; - Self-administered, validated, 96-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~10.4y of follow-up; - [underlined: Incident stroke (including subtypes):] Obtained via linkage with Swedish Hospital Discharge Registry; - [underlined: Total:] 1680 cases; - [underlined: Cerebral infarctions:] 1310 cases; - [underlined: Hemorrhagic strokes:] 233 cases, including 154 intracerebral hemorrhage cases and 79 subarachnoid hemorrhage cases; - [underlined: Unspecified stroke:] 137 cases | SFA; [underlined: Incident Total Stroke,] relative risk (RR) (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.62; [underlined: Incident Cerebral Infarction,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.55; [underlined: Incident Hemorrhagic Stroke,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.25; MUFA; [underlined: Incident Total Stroke,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.29; [underlined: Incident Cerebral Infarction,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.40; [underlined: Incident Hemorrhagic Stroke,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.46; PUFA; [underlined: Incident Total Stroke,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.43; [underlined: Incident Cerebral Infarction,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.36; [underlined: Incident Hemorrhagic Stroke,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.57; ALA; [underlined: Incident Total Stroke,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.16; [underlined: Incident Cerebral Infarction,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.22; [underlined: Incident Hemorrhagic Stroke,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.37; EPA+DHA; [underlined: Incident Total Stroke,] RR (95% CI); Q1 (ref) vs Q2: 0.93 (0.80, 1.08); Q1 (ref) vs Q3: 0.87 (0.74, 1.02); Q1 (ref) vs Q4: 0.89 (0.76, 1.05); Q1 (ref) vs Q5: 0.84 (0.72, 0.99); P-trend: 0.04; Per 500mg/d increase: 0.86 (0.75, 0.99); [underlined: Incident Cerebral Infarction,] RR (95% CI); Q1 (ref) vs Q2: 0.88 (0.74, 1.04); Q1 (ref) vs Q3: 0.84 (0.70, 1.01); Q1 (ref) vs Q4: 0.83 (0.69, 0.99); Q1 (ref) vs Q5: 0.83 (0.69, 0.99); P-trend: 0.06; [underlined: Incident Hemorrhagic Stroke,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, Q5: NS, P-trend: 0.16; n-6 PUFA; [underlined: Incident Total Stroke,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, Q5: NS, P-trend: 0.98; [underlined: Incident Cerebral Infarction,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.73; [underlined: Incident Hemorrhagic Stroke,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, Q5: NS, P-trend: 0.39; Cholesterol; [underlined: Incident Total Stroke,] RR (95% CI); Q1 (ref) vs Q2: 0.91 (0.76, 1.08); Q1 (ref) vs Q3: 1.15 (0.97, 1.37); Q1 (ref) vs Q4: 1.17 (0.98, 1.39); Q1 (ref) vs Q5: 1.20 (1.00, 1.44); P-trend: 0.01; Per 120mg/d increase: 1.15 (1.02, 1.31); [underlined: Incident Cerebral Infarction,] RR (95% CI); Q1 (ref) vs Q2: 0.95 (0.78, 1.15); Q1 (ref) vs Q3: 1.17 (0.96, 1.42); Q1 (ref) vs Q4: 1.19 (0.97, 1.45); Q1 (ref) vs Q5: 1.29 (1.05, 1.58); P-trend: 0.004; Per 120mg/d increase: 1.21 (1.05, 1.39); [underlined: Incident Hemorrhagic Stroke,] RR (95% CI); Q1 (ref) vs Q2, Q3, Q4, Q5: NS, P-trend: 0.77 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, TEI.; Key confounders accounted for: Sex, age, SES (education), smoking, alcohol intake, physical activity, family history of CVD or diabetes.; Additional model adjustments: BMI, history of hypertension, history of diabetes, aspirin use; Analyses of types of fat: cholesterol, other types of fat; Analyses of cholesterol: total fat.; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; Swedish Council for Working Life and Social Research; Karolinska Institutet Research Fellow grant
Levitan, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22172525) ^181^; PCS, SIMPLER: SMC (Swedish Mammography Cohort), Sweden; Baseline N=39,227, Analytic N=36,234 (Attrition: 8%); Participant characteristics at baseline:; - Women without history of MI, diabetes, or cancer (other than non-melanoma skin cancer) at baseline; - Age: Mean~62y; - Sex (female): 100%; - Race/ethnicity: NR; - SES: Education, ~75% less than high school, ~8% high school, ~17% university; - Anthropometry: BMI, Mean~25; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - History of high cholesterol: ~8%; - History of hypertension: ~20%; Summary of findings:; Among women, ALA and LA intake at ~62y of age was not significantly associated with incident heart failure during ~9y of follow-up. | Exposures:; - ALA (quintiles; g/d), Median (range):; - Q1 (ref): 0.88 (0.34-0.96); - Q2: 1.03 (0.97-1.09); - Q3: 1.15 (1.10-1.21); - Q4: 1.28 (1.22-1.36); - Q5: 1.50 (1.37-4.85); - LA (quintiles; g/d), Median (range):; - Q1 (ref): 4.6 (1.7-5.0); - Q2: 5.3 (5.1-5.6); - Q3: 5.9 (5.7-6.1); - Q4: 6.5 (6.2-7.0); - Q5: 7.8 (7.1-31.2); [underlined: Assessment method and timing]:; - Self-administered, validated, 96-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~9y of follow-up; - [underlined: Incident heart failure (HF; hospitalization or mortality):] Obtained via linkage with Swedish inpatient and cause-of-death registers; - [underlined: Total:] 651 cases (596 hospitalizations, 55 deaths) | ALA; [underlined: Incident HF,] Rate Ratio (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.41; LA; [underlined: Incident HF,] Rate Ratio (95% CI); Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.36; Associations did not vary by long-chain n-3 PUFA intake (ALA, P-interaction: 0.29; LA, P-interaction: 0.54). No interaction between ALA and LA (P-interaction: 0.81). | Key confounders [underlined: NOT] accounted for:; Race/ethnicity.; Key confounders accounted for: Sex, age, SES (education), TEI, smoking, alcohol intake, physical activity, family history of CVD or diabetes.; Additional model adjustments: BMI, fiber consumption, Na consumption, living alone, post-menopausal hormone use, self-reported history of hypertension, self-reported history of high cholesterol.; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of women with diabetes at baseline; - Did not account for co-exposures (other FAs); - No preregistered statistical analysis plan; Funding sources:; Swedish Research Council/Committee for Infrastructure and Council/Committee for Medicine; Swedish Foundation for International Cooperation in Research and Higher Education
Patterson, 2013 (https://www.ncbi.nlm.nih.gov/pubmed/23173172) ^194^; PCS, SIMPLER: SMC (Swedish Mammography Cohort), Sweden; Baseline N=39,227, Analytic N=33,636 (Attrition: 14%); Participant characteristics at baseline:; - Women without history of CVD, diabetes, or cancer at baseline; - Age: Mean~61y; - Sex (female): 100%; - Race/ethnicity: NR; - SES: Postsecondary-level education, ~20%; - Anthropometry: BMI, Mean~25; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - History of high cholesterol: ~7%; - History of hypertension: ~19%; Summary of findings:; Among women, butter intake at ~61y of age was not significantly associated with incident myocardial infarction during ~11.6y of follow-up. | Exposures:; - Butter (categorical):; - C1 (ref): No butter used on bread or in cooking; - C2: Butter used in cooking but not on bread; - C3: Butter used on bread but not in cooking; - C4: Butter used both on bread and in cooking; [underlined: Assessment method and timing]:; - Self-administered, validated, 96-item semi-quantitative FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~11.6y of follow-up; - [underlined: Incident MI (fatal and nonfatal):] Obtained via linkage with Swedish inpatient and cause-of-death registers; - [underlined: Total:] 1392 cases (including 254 fatal cases) | Butter; [underlined: Incident MI,] HR (95% CI); C1 (ref) vs C2, C3, or C4: All NS | Key confounders [underlined: NOT] accounted for:; Race/ethnicity.; Key confounders accounted for: Sex, age, SES (education), TEI, smoking, alcohol intake, physical activity, family history of CVD or diabetes.; Additional model adjustments: Waist-to-hip ratio, diagnosis of hypertension, diagnosis of high cholesterol, aspirin usage, hormone therapy usage, intake of milk, cultured milk/yogurt, cheese, and cream/crème fraiche, intake of fruit and vegetables, intake of whole-grain foods, use of oils in cooking, use of low-fat margarine on bread.; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of women with diabetes at baseline; - Butter intake categories not based on amount consumed; - No preregistered statistical analysis plan; Funding sources:; Swedish Council for Working Life and Social Research; Swedish Research Council/Infrastructure Medicine
Bergkvist, 2014 (https://www.ncbi.nlm.nih.gov/pubmed/24428778) ^146^; PCS, SIMPLER: SMC (Swedish Mammography Cohort), Sweden; Baseline N=39,227, Analytic N=34,591 (Attrition: 12%); Participant characteristics at baseline:; - Women without prevalent CVD or cancer at baseline; - Age: Mean~61y; - Sex (female): 100%; - Race/ethnicity: NR; - SES: Post-secondary education, ~20%; - Anthropometry: BMI, Mean~25; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - High cholesterol: ~7%; - Hypertension: ~19%; Summary of findings:; Among women, higher intake of DHA and EPA, after adjusting for PCB exposure, at ~61y of age was associated with lower risk of stroke during ~12y of follow-up. | Exposures:; - EPA + DHA (quartiles; mg/d), Median:; - Q1 (ref): 148; - Q2: 247; - Q3: 335; - Q4: 520; [underlined: Assessment method and timing]:; - Self-administered, validated, 96-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~12y of follow-up; - [underlined: Incident stroke:] Obtained via linkage with Swedish National Hospital Discharge and Cause of Death Registers; - [underlined: Total:] 2015 cases (1532 ischemic, 216 intracerebral hemorrhages, 94 subarachnoid hemorrhages, 173 unspecified) | EPA + DHA; [underlined: Incident Stroke,] Relative Risk (95% CI); Q1 (ref) vs Q2: 0.92 (0.78, 1.09); Q1 (ref) vs Q3: 0.89 (0.70,1.12); Q1 (ref) vs Q4: 0.72 (0.54, 0.96); P-trend: 0.014 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity.; Key confounders accounted for: Sex, age, SES (education), TEI, smoking, alcohol intake, physical activity, family history of CVD or diabetes.; Additional model adjustments: High cholesterol, history of hypertension, atrial fibrillation before baseline, use of postmenopausal hormones, use of aspirin, BMI, parity, use of fish oil supplements, consumption of fruit and vegetables, red and processed meat, and dairy products, dietary MeHg exposure, dietary PCB exposure; Limitations:; - Not all key confounders accounted for; - Did not account for co-exposures (other FAs); - No preregistered statistical analysis plan; Funding sources:; Swedish Research Council Formas; Swedish Research Council for Health, Working Life, and Welfare (Forte); Swedish Research Council/Committee for Infrastructure
Bergkvist, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/25679993) ^145^; PCS, SIMPLER: SMC (Swedish Mammography Cohort), Sweden; Baseline N=39,227, Analytic N=33,446 (Attrition: 15%); Participant characteristics at baseline:; - Women without prevalent CVD, diabetes, or cancer at baseline; - Age: Mean~61y; - Sex (female): 100%; - Race/ethnicity: NR; - SES: Post-secondary education, ~20%; - Anthropometry: WC <80cm, ~32%; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - High cholesterol: ~7%; - Hypertension: ~19%; Summary of findings:; Among women ~61y of age, moderate intake of DHA and EPA was significantly associated with lower risk of incident myocardial infarction (third quartile vs first quartile of intake), after adjustment for dietary PCB exposure, during ~12y of follow-up. The second and fourth quartile of DHA and EPA intake (compared to the first quartile) were not associated with incident myocardial infarction and there was not a statistically significant linear trend detected. | Exposures:; - EPA + DHA (quartiles; mg/d), Median:; - Q1 (ref): 148; - Q2: 247; - Q3: 334; - Q4: 518; [underlined: Assessment method and timing]:; - Self-administered, validated, 96-item FFQ representing intake during previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~12y of follow-up; - [underlined: Incident MI (fatal and nonfatal):] Obtained via linkage with Swedish National Hospital Discharge and Cause of Death Registers; - [underlined: Total:] 1386 cases (276 fatal cases) | EPA + DHA; [underlined: Incident MI,] Relative Risk (95% CI); Q1 (ref) vs Q2: 0.90 (0.73, 1.11); Q1 (ref) vs Q3: 0.74 (0.56, 0.98); Q1 (ref) vs Q4: 0.74 (0.52, 1.06); P-trend: 0.21 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity.; Key confounders accounted for: Sex, age, SES (education), TEI, smoking, alcohol intake, physical activity, family history of CVD or diabetes.; Additional model adjustments: Use of postmenopausal hormones, use of aspirin, WC, weight loss >5kg within a year, parity, use of fish oil supplements, consumption of fruit and vegetables, dairy products, red and processed meat, intake of SFA, dietary MeHg exposure, dietary PCB exposure.; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of women with diabetes at baseline; - No preregistered statistical analysis plan; Funding sources:; Swedish Research Council Formas; Swedish Research Council/Research Infrastructure; Swedish Council for Working Life and Social Research
Bergkvist, 2016 (https://pubmed.ncbi.nlm.nih.gov/26690540/) ^144^; PCS, SIMPLER: CSM (Cohort of Swedish Men), Sweden; Baseline N=48,850 Analytic N=36,759 (Attrition: 25%); Participant characteristics at baseline:; - 100% without prevalent CVD, diabetes or cancer; - Age: ~59y; - Sex (female): 0%; - Race/ethnicity: NR; - SES: Post-secondary education: 18%; - Anthropometry: WC <102 cm: ~77%; Fat intake at baseline, Mean:; - SFA: ~41 g/d; - EPA+DHA: ~0.46 g/d; Blood lipids and BP at baseline:; High cholesterol: ~8%; Hypertension: ~14%; Summary of findings:; Greater EPA+DHA intake was significantly associated with lower risk of myocardial infarction after adjusting for PCB exposure. | Exposures:; - EPA+DHA (continuous, g/d); [underlined: Assessment method and timing]:; - Self-administered, validated 96-item FFQ to assess usual food intake in previous 12mo; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 12 y of follow-up; - [underlined: Incident MI]: Swedish National Hospital Discharge Register, Cause of Death Register; - [underlined: MI:] 3,005 cases | [underlined: Incident MI], Relative Risk (RR) (95% CI); EPA+DHA; 0.67 (0.50, 0.90) P-trend=0.004 | Key confounders [underlined: NOT] accounted for:; Sex, race/ethnicity; Key confounders accounted for: Age, SES, TEI, physical activity, smoking, alcohol intake, family history of MI; Additional model adjustments: Dietary PCB exposure, high cholesterol, hypertension, use of aspirin, WC, use of fish oil supplements, consumption of fruit and vegetables, dairy products and red and processed meat, dietary intake of SFA, dietary MeHg exposure; Limitations:; - Not all key confounders adjusted for; - Potential selection bias due to excluding participants with diabetes; - Analyses did not account for co-exposures (MUFAs, other PUFAs); - No preregistered statistical analysis plan; Funding sources:; Swedish Research Council Formas; Swedish Council for Working Life and Social Research; Swedish Research Council/Research Infrastructure
Kippler, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/27473885) ^174^; PCS, SIMPLER: CSM (Cohort of Swedish Men), Sweden; Baseline N=48,850, Analytic N=39,948 (Attrition: 18%); Participant characteristics at baseline:; - No history of CVD or cancer; - Type 2 diabetes: ~8%; - Age: Mean~59y; - Sex (female): 0%; - Race/ethnicity: NR; - SES: ~18% University education; - Anthropometry: BMI, Mean~26; Fat intake at baseline:; - EPA/DHA (g/d): Mean=0.40; - Fish oil supplements: 4.5%; - SFA (g/d): Mean~44; BP at baseline:; - Hypertension: ~15%; Summary of findings:; Dietary EPA-DHA intake was associated with lower risk of hemorrhagic stroke, but not ischemic stroke after adjusting for PCB exposure over 12y follow-up among middle-aged Swedish men. | Exposures:; - EPA/DHA intake (quartiles, mg/d), Median; - Q1 0.18; - Q2 0.34; - Q3 0.46; - Q4 0.73; [underlined: Diet assessment method and timing]:; - 96-item FFQ used to assess food and beverage intake during the previous 12mo (validated); - Administered at baseline; Outcomes and assessment methods:; - Assessed during 12y of follow-up; - [underlined: Incident stroke events] ascertained by record linkage to medical and death registers.; - [underlined: Any stroke: 217 cases]; - [underlined: Ischemic stroke]: 2286 cases; - [underlined: Hemorrhagic stroke:] 474 cases | [underlined: Ischemic stroke,] HR (95% CI); EPA/DHA (quartiles); Q1 (ref) vs Q2, Q3, or Q4: All NS; P=0.14; [underlined: Hemorrhagic stroke,] HR (95% CI); EPA/DHA (quartiles); Q1 (ref) vs Q2: 0.84 (0.59–1.20); Q1 (ref) vs Q3: 0.57 (0.35–0.93); Q1 (ref) vs Q4: 0.42 (0.22–0.79); P<0.01; [underlined: Intracerebral hemorrhage,] HR (95% CI); Q1 (ref) vs Q2: 0.83 (0.56–1.22); Q1 (ref) vs Q3: 0.56 (0.33–0.96); Q1 (ref) vs Q4: 0.42 (0.21–0.85); P<0.01 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity; Key confounders accounted for: Age, sex, SES (education), TEI, smoking, alcohol intake, physical activity, family history of CVD; Additional model adjustments: Hypercholesterolemia, hypertension, atrial fibrillation, use of aspirin, BMI, use of fish oil supplements, intake of fruit and vegetables, intake of red and processed meat and dairy products, dietary intake of SFA and dietary MeHg exposure, and PCB exposure; Limitations:; - Not all key confounders accounted for; - Analyses did not account for co-exposures (other FA); - No preregistered statistical analysis plan; Funding sources:; Swedish Research Council Formas; the Swedish Research Council for Health, Working Life, and Welfare (Forte), and the Swedish Research Council/Committee for Infrastructure.
Akesson, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/30776745) ^137^; PCS, SIMPLER: SMC (Swedish Mammography Cohort) and CSM (Cohort of Swedish Men), Sweden; Baseline N=88,077, Analytic N=69,498 (Attrition: 21%); Participant characteristics at baseline:; - Men 45-79y of age and women 49-83y of age at baseline without previous diagnosis of cancer, CVD, or type 2 diabetes; - Age: Men~59y, Women~61y; - Sex (female): 47%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: WC >102cm (men), ~81%; WC>88cm (women), ~30%; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - High Cholesterol: ~8% men; ~7% women; - Hypertension: ~14% men; 19% women; Summary of findings:; In women, higher EPA/DHA intake, after adjusting for dietary PCB exposure, at ~61y of age was significantly associated with lower risk of incident HF after 12y of follow-up. In men, EPA/DHA intake, after adjusting for dietary PCB exposure, at ~59y of age was not significantly associated with risk of incident HF after 12y of follow-up. | Exposures:; - EPA/DHA (quintiles; mg/d), Mean (SD); - Q1: Men, 161 (81); Women, 132 (60); - Q2: Men, 300 (64); Women, 224 (48); - Q3: Men, 393 (64); Women, 286 (46); - Q4: Men, 501 (76); Women, 370 (60); - Q5: Men, 921 (59); Women, 646 (36); [underlined: Assessment method and timing]:; - Validated, semi-quantitative, 96-item FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed up to 12y of follow-up; - [underlined: Incident HF:] Obtained through linkage with Swedish National Patient Register and Swedish Cause of Death Register; - [underlined: Men:] 3128 cases; - [underlined: Women:] 2736 cases | [underlined: Incident HF,] Relative Risk (95% CI); Men:; Q1 (ref) vs Q2: 0.94 (NR); Q1 (ref) vs Q3: 0.80 (NR); Q1 (ref) vs Q4: 0.81 (NR); Q1 (ref) vs Q5: 0.82 (0.63, 1.07); P-trend: 0.19; Women:; Q1 (ref) vs Q2: 0.82 (NR); Q1 (ref) vs Q3: 0.79 (NR); Q1 (ref) vs Q4: 0.74 (NR); Q1 (ref) vs Q5: 0.71 (0.54, 0.93); P-trend: 0.035 | Key confounders [underlined: NOT] accounted for:; Alcohol intake.; Key confounders accounted for: Sex, age, race/ethnicity, SES (education), TEI, smoking, physical activity, family history of CVD or diabetes.; Additional model adjustments: WC, weight loss >5kg within 1y, high cholesterol, history of hypertension, aspirin use, Mediterranean diet score, methylmercury intake, dietary PCB exposure.; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of participants with type 2 diabetes; - No preregistered statistical analysis plan; Funding sources:; Swedish Research Council
Donat-Vargas, 2019 (https://www.ncbi.nlm.nih.gov/pubmed/31628875) ^158^; PCS, SIMPLER: SMC (Swedish Mammography Cohort) and CSM (Cohort of Swedish Men), Sweden; Baseline N=88,077, Analytic N=69,498 (Attrition: 21%); Participant characteristics at baseline:; - Men 45-79y of age and women 49-83y of age at baseline without previous diagnosis of cancer, CVD, or type 2 diabetes; - Age: Men~59y, Women~61y; - Sex (female): 47%; - Race/ethnicity: NR; - SES: Postsecondary education, ~19%; - Anthropometry: WC >102cm (men), ~81%; WC>88cm (women), ~30%; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - High Cholesterol: ~8% men; ~7% women; - Hypertension: ~14% men; 19% women; Summary of findings:; In men and women, higher intake of EPA/DHA at ~60y of age was associated with lower risk of CVD mortality during ~15.5y of follow-up. | Exposures:; - EPA/DHA (quintiles; mg/d), Median; - Q1: Men, 157; Women, 133; - Q2: Men, 296; Women, 223; - Q3: Men, 394; Women, 286; - Q4: Men, 497; Women, 364; - Q5: Men, 780; Women, 551; [underlined: Assessment method and timing]:; - Validated, semi-quantitative, 96-item FFQ assessing intake during the previous year; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~15.5y of follow-up; - [underlined: CVD Mortality:] Obtained through linkage with Swedish Cause of Death Register; - [underlined: Total:] 6338 cases | [underlined: CVD Mortality,] HR (95% CI); Q1 (ref) vs Q2: 0.89 (0.80, 0.99); Q1 (ref) vs Q3: 0.87 (0.76, 0.99); Q1 (ref) vs Q4: 0.82 (0.70, 0.95); Q1 (ref) vs Q5: 0.79 (0.66, 0.95); P-trend: 0.041 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, alcohol intake.; Key confounders accounted for: Sex, age, SES (education), TEI, smoking, physical activity, family history of CVD or diabetes.; Additional model adjustments: WC, hypertension, hypercholesterolemia, weight loss >5kg within 1y, use of aspirin, Mediterranean diet, parity use of hormone replacement therapy, dietary methylmercury exposure, PCB exposure; Limitations:; - Not all key confounders accounted for; - Potential selection bias due to exclusion of participants with diabetes; - Analyses did not account for co-exposures (other FA); - No preregistered statistical analysis plan; Funding sources:; Swedish Research Council
Santiago, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/29582893) ^204^; PCS, SUN, Spain; Baseline N=21,678, Analytic N=19,341 (Attrition: 11%); Participant characteristics at baseline:; - No history of CVD; - Diabetes: ~1.7%; - Age: ~37.5y; - Sex (female): 43%; - Race/ethnicity: NR; - SES: Years of higher education: ~5; - Anthropometry: Mean BMI: ~23.5; Fat intake at baseline, Mean:; - SFA (%E): ~12.5; - MUFA (%E): ~15.5; - PUFA (%E): ~5.3; - Cholesterol (mg): ~450; BP at baseline:; - Hypertension: ~7.8%; Summary of findings:; Saturated, polyunsaturated and monounsaturated fat intake and replacement of 5% saturated fat with MUFA, PUFA, carbohydrate or refined carbohydrate were not associated with CVD incidence during 10 years of follow-up. | Exposures:; - SFA intake (tertiles, %E SFA), Median; - T1 9.6; - T2 12.4; - T3 15.4; - MUFA intake (tertiles, %E MUFA), Median; - T1 12.5; - T2 15.5; - T3 19.0; - PUFA intake (tertiles, %E PUFA), Median; - T1 3.8; - T2 5.0; - T3 6.6; - Replacement of SFA with MUFA, PUFA, CHO or refined CHO (per 5%E); [underlined: Diet assessment method and timing]:; - Self-administered semi-quantitative 136-item FFQ (validated); - Administered at baseline; Outcomes and assessment methods:; - Assessed during median 10.10y of follow-up; - [underlined: Composite of incident non-fatal acute coronary syndromes (myocardial infarction with or without ST elevation), non-fatal stroke or cardiovascular death] ascertained via self-report and subsequent medical record review; deaths reported by next of kin/associates, postal authorities and National Death Record.; - [underlined: Incident cases of CVD]: 140 cases | [underlined: Incident CVD], HR (95% CI); SFA (tertiles); T1 (ref) vs T2, or T3: All NS; P-trend: 0.356; MUFA (tertiles); T1 (ref) vs T2, or T3: All NS; P-trend: 0.805; PUFA (tertiles); T1 (ref) vs T2, or T3: All NS; P-trend: 0.13; Replace SFA:; With MUFA: 1.40 (0.75, 2.61); NS; With PUFA: 1.30 (0.64, 2.63) NS; With CHO: 1.23 (0.84, 1.97) NS; With refined CHO: 1.14 (0.74, 1.78) NS. | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, alcohol intake; Key confounders accounted for: Age, sex, SES (education), TEI, smoking, physical activity, family history of CVD or diabetes; Additional model adjustments: BMI, following special diets, weight gain in the past 5y, marital status, prevalent or previous angina pectoris or revascularization procedures, prevalent diabetes, prevalent hypertension, prevalent hypercholesterolemia, prevalent hypertriglyceridemia and prevalent depression; Limitations:; - Not all key confounders accounted for; - Analyses did not account for co-exposures (types of fat); - No preregistered statistical analysis plan; Funding sources:; Spanish Ministry of Health –Instituto de Salud Carlos III and European Regional Development Fund; the Navarra Regional Government; the University of Navarra.
Nagata, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22810986) ^186^; PCS, Takayama Study, Japan; Baseline N=31,552, Analytic N=28,356 (Attrition: 10%); Participant characteristics at baseline:; - Adults ≥35y of age without history of MI, stroke, or cancer at baseline; - Age: Mean~54y; - Sex (female): 54%; - Race/ethnicity: NR; - SES: Years of education: ≤11y ~60%, 12-14y ~30%, ≥15y ~12% men, 4% women; - Anthropometry: BMI, Mean~22; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids and BP at baseline:; - NR; Summary of findings:; In men and women intake of SFA, MUFA, PUFA, and long chain n-3 PUFA, at ~54y of age was not significantly associated with CVD mortality during ~16y of follow-up. | Exposures:; - SFA (quintiles; %E), Medians:; - Q1: 4.2 (men), 4.4 (women); - Q2: 5.4 (men), 5.7 (women); - Q3: 6.2 (men), 6.6 (women); - Q4: 7.1 (men), 7.4 (women); - Q5: 8.7 (men), 8.8 (women); - MUFA (quintiles; %E), Medians:; - Q1: 5.3 (men), 5.4 (women); - Q2: 6.7 (men), 6.9 (women); - Q3: 7.7 (men), 7.9 (women); - Q4: 8.8 (men), 8.9 (women); - Q5: 10.4 (men), 10.4 (women); - PUFA (quintiles; %E), Medians:; - Q1: 4.2 (men), 4.4 (women); - Q2: 5.1 (men), 5.4 (women); - Q3: 5.8 (men), 6.0 (women); - Q4: 6.6 (men), 6.7 (women); - Q5: 7.7 (men), 7.8 (women); - Long chain n-3 PUFA (quintiles; %E), Medians:; - Q1: 0.15 (men), 0.13 (women); - Q2: 0.22 (men), 0.20 (women); - Q3: 0.28 (men), 0.25 (women); - Q4: 0.37 (men), 0.32 (women); - Q5: 0.56 (men), 0.47 (women); [underlined: Assessment method and timing]:; - 169-item FFQ (validated); - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~16y of follow-up; - [underlined: CVD mortality:] Obtained through death certificates from public health centers | [underlined: CVD Mortality,] HR (95% CI); SFA; Men and Women:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.680 (men), 0.13 (women); MUFA; Men and Women:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.65 (men), 0.35 (women); PUFA; Men and women:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.11 (men), 0.45 (women); Long chain n-3 PUFA; Men and Women:; Q1 (ref) vs Q2, Q3, Q4, or Q5: All NS; P-trend: 0.65 (men), 0.27 (women) | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, family history of CVD or diabetes; Key confounders accounted for: Sex, age, SES (education), non-alcohol TEI, smoking, alcohol intake, physical activity; Additional model adjustments: Height, BMI, marital status, history of diabetes and hypertension, protein intake, consumption of dietary fiber, vegetables and fruit, fat subtypes as appropriate; Limitations:; - Not all key confounders accounted for; - Potential for selection bias due to exclusion of participants who died within the first 3y of follow-up; - No preregistered statistical analysis plan; Funding sources:; Ministry of Education, Science, Sports and Science and Technology, Japan
Isaksen, 2018 (https://www.ncbi.nlm.nih.gov/pubmed/30656277) ^169^; PCS, Tromso Study, Norway; Baseline N=29,648, Analytic N=21,970 (Attrition: 26%); Participant characteristics at baseline:; - No history of VTE; - Age: ~46y; - Sex (female): 51.4%; - Race/ethnicity: NR; - SES: Education: ~37% Higher education; - Anthropometry: Mean BMI: ~25; Fat intake at baseline:; - n-3PUFA (g/week): Median=11.1; Blood lipids and BP at baseline, Mean:; - TC (mmol/L): ~5.8; - HDL (mmol/L): ~1.5; - Triglycerides (mmol/L): ~1.5; - SBP (mmHg): ~134; - DBP (mmHg): ~77; Summary of findings:; Dietary intake of marine n-3 PUFAs ≥4.7g/week was associated with a lower risk of venous thromboembolism during 11.6 years of follow-up. There was no evidence of additional protection with increased intake above that threshold level. | Exposures:; - EPA+DHA intake from fish and supplements (quartiles, g/week), Range; - Q1 <4.7; - Q2 4.7-13.4; - Q3 13.4-29.1; - Q4 >29.1; [underlined: Diet assessment method and timing]:; - Self-administered questionnaires used to assess intake of lean and fat fish, fish spread and supplements containing n-3 PUFA; - Administered prior to baseline; Outcomes and assessment methods:; - Assessed during median 11.60y of follow-up; - [underlined: risk of venous thromboembolism] ascertained via hospital discharge, radiology procedure and autopsy registries; - [underlined: Risk of venous thromboembolism]: 541 cases | [underlined: Risk of venous thromboembolism,] HR (95% CI); EPA+DPA+DHA from diet and supplements (quartiles); Q1 (ref) vs Q2: 0.74 (0.57-0.96); Q1 (ref) vs Q3: 0.77 (0.59-0.99); Q1 (ref) vs Q4: 0.78 (0.61-1); P=0.13 | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, SES, TEI, smoking, alcohol intake, physical activity, family history of CVD or diabetes; Key confounders accounted for: Age, sex; Additional model adjustments: BMI; Limitations:; - Not all key confounders accounted for; - Self-administered questionnaire used to assess EPA/DHA was not validated; - Analyses did not account for co-exposures (SFA, MUFA, PUFA); - Potential missing data bias due to not statistically accounting for missing data; - No preregistered statistical analysis plan; Funding sources:; Stiftelsen Kristian Gerhard Jebsen; UiT The Arctic University of Norway
Blekkenhorst, 2015 (https://www.ncbi.nlm.nih.gov/pubmed/25948671) ^147^; PCS, unnamed cohort, Australia; Baseline N=1,500, Analytic N=1,469 (Attrition: 2%); Participant characteristics at baseline:; - Prevalent atherosclerotic vascular disease (%): 11.9; - Type 2 diabetes: 6.1%; - Age: Mean=75.2y; - Sex (female): 100%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: Mean BMI: 27.2; Fat intake at baseline, Mean (SD):; - SFA (g/d): 25.3 (11.3); - MUFA (g/d): 22.4 (8.7); - PUFA (g/d): 10.8 (4.8); Blood lipids at baseline, Mean:; - TC (mmol/L): 5.9; - LDL (mmol/L): 3.7; - HDL (mmol/L): 1.4; - Triglycerides (mmol/L): 1.6; Summary of findings:; Dietary intake of saturated fat was associated atherosclerotic vascular disease mortality in elderly women from Australia. | Exposures:; - SFA intake, (continuous, per SD); - SFA intake, (quartiles, g/d); - Q1: < 17.39; - Q2: 17.39–23.40; - Q3: 23.41–31.28; - Q4: >31.28; [underlined: Diet assessment method and timing]:; - Self-administered, semi-quantitative 74-item FFQ (validated) assessing intake over 12mo; - Administered at baseline; Outcomes and assessment methods:; - Assessed during median 5y of follow-up; - [underlined: Atherosclerotic vascular disease (ASVD) mortality] (including ischemic heart disease; cerebrovascular disease, excluding hemorrhage; heart failure; and peripheral arterial disease) ascertained via death records; - [underlined: Total]: 134 cases | [underlined: SFA]; [underlined: Atherosclerotic vascular disease mortality,] HR (95% CI); Saturated fat (per SD, 11.26g/d); Per 1 SD: 1.77 (1.31, 2.37), P<0.001; Saturated fat (quartiles); Q1 (ref) vs Q2: 1.28 (0.74, 2.21), P=0.37; Q1 (ref) vs Q3: 1.35 (0.74, 2.45), P=0.327; Q1 (ref) vs Q4: 3.07 (1.54, 6.11), P=0.001 | Key confounders [underlined: NOT] accounted for:; SES, race/ethnicity, smoking, alcohol intake, family history of CVD or diabetes; Key confounders accounted for: Age, sex, physical activity, TEI; Additional model adjustments: BMI, prevalent diabetes, renal function, statin medication, prevalent ASVD, low-dose aspirin medication, antihypertensive medication; Limitations:; - Not all key confounders accounted for and no adjustment made for time-varying confounding; - No preregistered statistical analysis plan; Funding sources:; National Health and Medical Research Council; Raine Medical Research Foundation
Bell, 2014 (https://www.ncbi.nlm.nih.gov/pubmed/24496442) ^142^; PCS, VITAL (Vitamins and Lifestyle Study), U.S.; Baseline N=77,718, Analytic N=70,495 (Attrition: 9%); Participant characteristics at baseline:; - Age: Range 50-76y; - Sex (female): ~50%; - Race/ethnicity: >90% White; - SES: Education: >31-48% College or advanced degree, 35-42% some college/technical school, 13-27% secondary school; - Anthropometry: ~10%≥30 ~30% 25-<30; Fat intake at baseline:; - Supplement intake (% subjects); - Low (0–4 d/week or <3 years): 5.6%; - High (≥4 d/week for ≥3 years): 4.3%; Blood lipids and BP at baseline: NR; Summary of findings:; Dietary EPA and DHA intake from diet and supplements was not associated with CVD mortality or Intracerebral hemorrhage in middle aged and older Americans during 5y follow-up. | Exposures:; - EPA+DHA intake from diet and supplements (quartiles, g), Range; - Q1 (0–0.082); - Q2 (0.083–0.174); - Q3 (0.175–0.322); - Q4 (>0.322); [underlined: Diet assessment method and timing]:; - 120-item semi-quantitative FFQ with special emphasis on measurement of micronutrient fortified foods, dietary fats and dark fish; - Self-report frequency and duration of n-3 supplement use over 10y.; - Intake estimate: (0.64 g/day for EPA and 0.35 g/day for DHA), multiplied by 10-y average use (days per week/7 × years/10); - Administered prior to baseline; Outcomes and assessment methods:; - Assessed during mean 5y of follow-up; - [underlined: CVD deaths] ascertained by record linkage to Washington State death records, Social Security Death Index, next of kin or the Surveillance, Epidemiology and End Results cancer registry for western Washington.; - [underlined: CVD death]: 769 cases | [underlined: CVD death,] HR (95% CI); EPA+DHA from diet and supplements (quartiles); Q1 (ref) vs Q2, Q3, or Q4: All NS; P=0.799; [underlined: Ischemic heart disease mortality,] HR (95% CI); EPA+DHA from diet and supplements (quartiles); Q1 (ref) vs Q2, Q3, or Q4: All NS, P=0.12 | Key confounders [underlined: NOT] accounted for:; None; Key confounders accounted for: Age, sex, race/ethnicity, SES (education), TEI, smoking, alcohol intake, physical activity, family history of CVD or diabetes; Additional model adjustments: BMI, fruit and vegetable intake, use of nonsteroidal anti-inflammatory drugs, aspirin, cholesterol lowering drugs, cancer screening, self-reported health, morbidity score, trans fat, SFA, fruit and vegetable intake, hormone therapy, age at menopause, AA intake; Limitations:; - Analyses did not account for co-exposures (MUFA, PUFA); - Potential bias in classification of exposures due to use of non-validated FFQ; - Potential missing data bias due to not statistically accounting for missing data; - No preregistered statistical analysis plan; Funding sources:; National Cancer Institute and the Office of Dietary Supplements, National Institutes of Health
Belin, 2011 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3127501/) ^140^; PCS, WHI-OS (Women’s Health Initiative), U.S.; Baseline N=93,676 Analytic N=79,752 (Attrition: 15%); Participant characteristics at baseline:; - 100% without prevalent CVD; - Age: ~64y (range: 50-79 y); - Sex (female): 100%; - Race/ethnicity: African American ~7%; - SES: Education: ≤High school diploma/GED ~20%, Some school after high school ~37%, College graduate ~42%; - Anthropometry: BMI~26; Fat intake at baseline, Mean:; - Total SFA: ~10%E; - MUFA: ~11%E; - PUFA: ~6%E; - Cholesterol: ~119 mg/day; - Trans FA: ~2%E; Blood lipids and BP at baseline, Mean:; - HDL: ~60 mg/dL; - LDL: ~123 mg/dL; - Triglycerides: ~133 mg/dL; - SBP: ~125 mmHg; Summary of findings:; Lower dietary cholesterol intake was significantly associated with lower incidence of CVD and HF in women. No significant associations were observed with SFA and PUFA:SFA ratio with CVD and HF incidence. | Exposures:; - SFA (categorical; >8.78%E (ref) vs ≤8.78%E); - Cholesterol (categorical; >232.14 mg (ref) vs ≤232.14 mg); - PUFA:SFA (categorical; <0.77 (ref) vs ≥0.77; [underlined: Assessment method and timing]:; - Self-administered, validated 131-item FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during mean of 10 y of follow-up; - [underlined: Incident cardiovascular disease (CVD; nonfatal myocardial infarction, coronary heart disease death, stroke, coronary revascularization, and incident HF):] Assessed by physician diagnosis and/or medical records; - [underlined: CVD:] 6,006 cases; - [underlined: HF:] 1,836 cases | [underlined: Incident CVD,] HR (95% CI); SFA: NS; Cholesterol: 0.89 (0.83, 0.95), P<0.001; PUFA:SFA: NS; [underlined: Incident HF,] HR (95% CI); SFA: NS; Cholesterol: 0.82 (0.73, 0.92), P<0.001; PUFA:SFA: NS | Key confounders [underlined: NOT] accounted for: Family history of CVD or diabetes; Key confounders accounted for: Sex, age, race/ethnicity, SES (educational level), TEI, alcohol intake, physical activity, smoking; Additional model adjustments: BMI, diabetes medication, taking pills for hypertension ever, and ever taking pills for cholesterol; Limitations:; - Not all key confounders adjusted for; - Analyses did not account for co-exposures (other types of fats); - No statistics to account for missing data; - No preregistered statistical analysis plan; Funding sources:; NHLBI, NIH, U.S. Department of Health and Human Services
Belin, 2011a (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3310223/) ^141^; PCS, WHI-OS (Women’s Health Initiative), U.S.; Baseline N=93,676 Analytic N=84,493 (Attrition: 10%); Participant characteristics at baseline:; - 100% without prevalent stroke or transient ischemic attack; - Age: ~63y (range: 50-79 y); - Sex (female): 100%; - Race/ethnicity: White 84%, African American 7%, Hispanic 4%, Other 5%; - SES: Education: Did not complete high school 5%, high school/GED 16%, Some training after high school 36%, College graduate 43%; - Anthropometry: BMI~27; Fat intake at baseline, Median:; - SFA: ~10%E; - LA: ~5.5%E; - ALA: ~0.67%E; - DHA+EPA: ~0.08%E; - Trans FA: ~2%E; Blood lipids and BP at baseline, Mean:; - HDL cholesterol: ~63 mg/dL; - Triglycerides: ~153 mg/dL; - SBP: ~127 mmHg; Summary of findings:; EPA+DHA intake and ALA intake were not associated with incidence of heart failure. | Exposures:; - EPA+DHA (quartile; Intake g/1000kcal Q1 0-0.02, Q2 0.021-0.04, Q3 0.041-0.07, Q4 0.071-0.17); - ALA (quartile; Intake g/1000kcal Q1 0.01-0.4, Q2 0.41-0.6, Q3 0.61-0.7, Q4 0.71-1.0); [underlined: Assessment method and timing]:; - Self-administered, validated WHI FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during mean of 10 y of follow-up; - [underlined: Incident heart failure (HF):] annual medical history | [underlined: Incident heart failure,] HR (95% CI); EPA+DHA: Q1 vs Q2, Q3, Q4: All NS; P-trend=NS; ALA: Q1 vs Q2, Q3, Q4: All NS; P-trend=NS | Key confounders [underlined: NOT] accounted for:; TEI, family history of CVD or diabetes; Key confounders accounted for: Sex, age, race/ethnicity, SES (education), alcohol intake, physical activity, smoking; Additional model adjustments: BMI, Diabetes, hypertension, AF, MI/CABG/PTCA, time-dependent MI, intake of fiber, fruit/vegetables, SFA, TFA, ALA, and LA; Limitations:; - Not all key confounders adjusted for; - No preregistered statistical analysis plan; Funding sources:; NHLBI; NIH; U.S. Department of Health and Human Services
Yaemsiri, 2012 (https://pubmed.ncbi.nlm.nih.gov/22383309/) ^220^; PCS, WHI-OS (Women’s Health Initiative), U.S.; Baseline N=93,676 Analytic N=87,025 (Attrition: 7%); Participant characteristics at baseline:; - 100% without prevalent stroke or transient ischemic attack; - Age: ~63y (range: 50-79 y); - Sex (female): 100%; - Race/ethnicity: White 84%, African American 7%, Hispanic 4%, Other 5%; - SES: Education: Did not complete high school 5%, high school/GED 16%, Some training after high school 36%, College graduate 43%; - Anthropometry: BMI: Mean=27, SD=6; Fat intake at baseline, Median:; - SFAs: ~14 g/d; - MUFA: ~17 g/d; - PUFA: ~9 g/d; - Cholesterol: ~163 mg/d; - Trans FA: ~2 g/day; BP at baseline, Mean (SD):; - SBP (mmHg): 126 (18); - DBP (mmHg): 75 (9); Summary of findings:; Higher dietary cholesterol (145 mg/day) intake, compared to 133 mg/day, was significantly associated with higher incidence of ischemic stroke, but was no longer significant when comparing higher quintiles of cholesterol intake. SFA, MUFA, and PUFA were not significantly associated with incidence of ischemic stroke. | Exposures:; - SFA (categorical, quintiles; Median intake (g/d) Q1 (ref) 12.9, Q2 13.4, Q3 14.5, Q4 17.0, Q5 26.1); - MUFA (categorical, quintiles; Median intake (g/d) Q1 (ref) 14.9, Q2 15.6, Q3 16.7, Q4 19.8, Q5 28.9); - PUFA (categorical, quintiles; Median intake (g/d) Q1 (ref) 8.4, Q2 8.4, Q3 9.0, Q4 10.6, Q5 16.0); - Cholesterol (categorical, quintiles; Median intake (mg/day) Q1 (ref) 133, Q2 144, Q3 163, Q4 203, Q5 311); [underlined: Assessment method and timing]:; - Self-administered, validated WHI 122-item FFQ; - Assessed at baseline and 3 y follow-up; Outcomes and assessment methods:; - Assessed during mean of ~7.6 y of follow-up; - [underlined: Incident ischemic stroke:] annual medical history; - [underlined: Ischemic stroke:] 1,049 cases | [underlined: Incident ischemic stroke,] HR (95% CI); SFA: NS; MUFA: NS; PUFA: NS; Cholesterol:; Q1 (ref) vs Q2: 1.32 (1.06, 1.65); Q1 (ref) vs Q3, Q4, Q5: All NS; P-trend=NS | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes; Key confounders accounted for: Sex, age, race/ethnicity, SES, TEI, alcohol intake, physical activity, smoking; Additional model adjustments: Hormone replacement therapy use, history of diabetes, aspirin use, use of antihypertensive medication, use of cholesterol-lowering medication, BMI, SBP, dietary vitamin E, fruits/vegetables, and fiber intake, history of CHD, atrial fibrillation; Limitations:; - Not all key confounders adjusted for; - Analyses did not account for co-exposures (other types of fats); - No preregistered statistical analysis plan; Funding sources:; NHLBI; NIH; U.S. Department of Health and Human Services; National Institute of Neurological Disorders and Stroke; AHA
Akbaraly, 2011 (https://www.ncbi.nlm.nih.gov/pubmed/21613557) ^136^; PCS, Whitehall II, United Kingdom; Baseline N=10,308, Analytic N=7319 (Attrition: 29%); Participant characteristics at baseline:; - Men and women 35-55y of age at baseline; - Age: ~50y; - Sex (female): ~30%; - Race/ethnicity: ~92% White, ~5% South Asian, ~3% Black; - SES: Occupational grade, ~15% Low, ~46% Intermediate, ~39% High; - Anthropometry: BMI, ~4% <20, ~49% 20-25, ~38% 25-30, ~9% ≥30; Fat intake at baseline, Mean (SD):; - PUFA:SFA (AHEI score): 5.2 (2.7) (score of 0 indicates least healthy dietary behavior, 10 indicates recommendations were fully met); Blood lipids and BP at baseline:; - Dyslipidemia: ~59%; - Hypertension: ~19%; Summary of findings:; In men and women, higher intake scores on the AHEI for PUFA:SFA ratio at ~50y of age was not significantly associated with CVD mortality during ~17.7y of follow-up. | Exposures:; - PUFA:SFA ratio (continuous; per 1 SD increase in AHEI component score); [underlined: Assessment method and timing]:; - Semi-quantitative, 127-item FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during ~17.7y of follow-up; - [underlined: CVD mortality:] Obtained through linkage with National Health Services death and electronic patient records; - [underlined: Total:] 141 cases (74 CHD, 28 stroke) | PUFA:SFA ratio; [underlined: CVD Mortality,] HR (95% CI); 1.02 (0.86, 1.22), P=0.79 | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes; Key confounders accounted for: Sex, age, race/ethnicity, SES (occupational grade), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments: Modified total AHEI score excluding PUFA:SFA ratio component, marital status, BMI, prevalent CVD, type 2 diabetes, hypertension, dyslipidemia, metabolic syndrome, inflammatory markers; Limitations:; - Not all key confounders accounted for; - No indication that FFQ was validated; - No information on other types of fat; - Those excluded due to missing data were older, more likely to be women, and to have a lower occupational grade; - No preregistered statistical analysis plan; Funding sources:; British Medical Research Council; British Heart Foundation; British Health and Safety Executive; British Department of Health; NHLBI; NIA; Agency for Health Care Policy and Research
Rhee, 2017 (https://pubmed.ncbi.nlm.nih.gov/27646568/) ^200^; PCS, WHS (Women’s Health Study), U.S.; Baseline N=39,876 Analytic N=38,392 (Attrition: 4%); Participant characteristics at baseline:; - 100% without prevalent CVD; - Age: ~54y; - Sex (female): 100%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI~26; Fat intake at baseline, Mean:; - PUFA:SFA: ~0.6; Blood lipids and BP at baseline:; - Hypertension: ~25%; - High cholesterol: ~29%; Summary of findings:; There were no significant associations between energy-adjusted ALA and marine omega-3 fatty acids and risk of major CVD, MI, ischemic stroke, total stroke, and CVD death. | Exposures:; - ALA (categorical, quintiles; Median intake (%E): Q1 (ref) 0.74, Q2 0.88, Q3 0.99, Q4 1.12, Q5 1.36); - Marine omega-3 fatty acids (categorical, quintiles; Median intake (%E): Q1 (ref) 0.06, Q2 0.11, Q3 0.16, Q4 0.25, Q5 0.40); [underlined: Assessment method and timing]:; - Self-administered, validated 131-item FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during mean of 21 y of follow-up; - [underlined: Incident major cardiovascular disease (CVD; nonfatal myocardial infarction, nonfatal stroke, cardiovascular death):] follow-up, medical records, review of autopsy reports, death certificates, medical records or next of kin or family members; - [underlined: Major CVD event:] 1,941 cases; - [underlined: Nonfatal MI:] 745 cases; - [underlined: Ischemic stroke:] 659 cases; - [underlined: Total stroke:] 987 cases; - [underlined: Cardiovascular deaths:] 501 cases | [underlined: Incident major CVD,] HR (95% CI); ALA: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=NS; Marine omega-3 FA: Q1 (ref) vs Q2, Q3, Q4,; Q5: All NS; P-trend=NS; [underlined: Incident MI,] HR (95% CI); ALA: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=NS; Marine omega-3 FA: Q1 (ref) vs Q2, Q3, Q4,; Q5: All NS; P-trend=NS; [underlined: Incident ischemic stroke,] HR (95% CI); ALA: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=NS; Marine omega-3 FA: Q1 (ref) vs Q2, Q3, Q4,; Q5: All NS; P-trend=NS; [underlined: Incident total stroke,] HR (95% CI); ALA: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=NS; Marine omega-3 FA: Q1 (ref) vs Q2, Q3, Q4,; Q5: All NS; P-trend=NS; [underlined: Incident CVD death,] HR (95% CI); ALA: Q1 (ref) vs Q2, Q3, Q4, Q5: All NS; P-trend=NS; Marine omega-3 FA: Q1 (ref) vs Q2, Q3, Q4,; Q5: All NS; P-trend=NS | Key confounders [underlined: NOT] accounted for:; Race/ethnicity, TEI; Key confounders accounted for: Sex, age, SES (educational level), alcohol intake, physical activity, smoking, family history of MI; Additional model adjustments: BMI, Randomized treatment, intake of dietary fiber, fruits and vegetables, trans fat, sodium, PUFA:SFA, oral contraceptive use, use of hormones as defined under hormone replacement therapy, multivitamin use, baseline history of hypertension, high cholesterol and diabetes; Limitations:; - Not all key confounders accounted for; - No preregistered statistical analysis plan; Funding sources:; NIH

* Abbreviations: AHEI – Alternative Healthy Eating Index, BP – blood pressure, CHO – carbohydrate, CI – confidence interval, d – day(s), DBP – diastolic blood pressure, FA – fatty acids, HDL – HDL cholesterol, HR – hazard ratio, IQR – interquartile range, LDL – LDL cholesterol, NR – not reported, NS – non significant, %E – percent energy, ref – reference group, SBP – systolic blood pressure, SD – standard deviation, SE – standard error, SEM – standard error of the mean, SES – socioeconomic status, TC – total cholesterol, TEI – total energy intake, WC – waist circumference, y – year(s)

† Statistically significant results bolded.

Table 9 Evidence from nested case-control studies examining types of dietary fat consumed by adults and cardiovascular disease endpoint outcomes^*^

Study and Population Characteristics | Exposures, Comparators and Outcomes | Results^†^ | Key Confounders, Study Limitations
Juan, 2018 (https://pubmed.ncbi.nlm.nih.gov/29722844) ^172^; Nested case-control, NHS and HPFS, U.S.; Baseline N=51,051 Analytic N=2,288 Subset of sample who provided blood samples: 720 Cad cases; 1568 CAD-free controls; Participant characteristics at baseline:; - 100% without prevalent CVD or cancer; - Cases and controls matched on age, smoking status, fasting status at blood draw, time of blood draw; - Age: NR; - Sex (female): NHS: 100%; NHS: 0%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: NR; Fat intake at baseline:; See “Results”; Blood lipids and BP at baseline: NR; Summary of findings:; LA, ALA, DHA, EPA or AA intake at baseline did not differ between CAD cases and controls. | Exposures:; - LA intake (mg/day); - ALA intake (mg/day); - DHA intake (mg/day); - EPA intake (mg/day); - AA intake (mg/day); [underlined: Assessment method and timing:]; - Self-administered, validated semi-quantitative FFQ; - Assessed at baseline (at blood draw, NHS: 1986, 1990; HPFS: 1990, 1994); Outcomes and assessment methods:; - Assessed during follow-up; - [underlined: Incident coronary artery disease (CAD):] medical records, phone interview or letter (classified as probable), reports from next of kin, U.S. postal system, certificates from vital statistics departments and National Death Index, autopsy (previously reported); - [underlined: CAD deaths:] 720 cases | [underlined: Incident CAD], Mean (SD), Cases vs Controls; NHS:; [underlined: LA (mg/d):]; 10.812.4(4247.4) vs 10,772.1 (3912.5), P=NS; [underlined: ALA (mg/d):]; 987.1 (402.6) vs 966.2 (384.0), P=NS; [underlined: DHA (mg/d):]; 152.5 (109.6) vs 154.5 (115.3), P=NS; [underlined: EPA (mg/d):]; 76.0(63.3) vs 79.8 (102.8), P=NS; [underlined: AA (mg/d):]; 74.1(29.3) vs 74.9 (29.5), P=NS; HPFS:; [underlined: LA (mg/d):]; 11,302.2 (4,451.2) vs 11,029.8 (4175.8), P=NS; [underlined: ALA (mg/d):]; 1084.3 (424.6) vs 1062.9 (397.7), P=NS; [underlined: DHA (mg/d):]; 166.1(136.9) vs 168.1 (145.3), P=NS; [underlined: EPA (mg/d):]; 99.0 (140.7) vs 101.6 (138.5), P=NS; [underlined: AA (mg/d):]; 81.4(33.0) vs 79.5 (33.8), P=NS | Key confounders NOT accounted for:; Sex, age, race/ethnicity, SES, TEI, alcohol intake, physical activity, smoking, family history of CVD or diabetes; Key confounders accounted for:; None; Additional model adjustments:; Energy contribution from protein, cholesterol intake, BMI, use of vitamins and aspirin, presence of baseline hypercholesterolemia, dietary intake of fruits and vegetables; Limitations:; - Not all key confounders accounted for; - Analyses did not account for coexposure (other types of fats); - No information on missing data; - No preregistered statistical analysis plan; Funding sources:; NCI, NHLBI
Pierucci, 2012 (https://pubmed.ncbi.nlm.nih.gov/21482083/) ^195^; NCC, ONCONUT, Italy; Baseline N=8,026 Analytic N=291 Cases: 97; Controls: 194; Participant characteristics at baseline:; - 100% without prevalent MI and diabetes; - Age: ~67 y; - Sex (female): ~40%; - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI~26; Fat intake at baseline, Mean:; - SFA: ~19 g/d; - MUFA: ~38 g/d; - PUFA: ~8 g/d; - Cholesterol: ~172 mg/d; BP at baseline:; - Hypertension: ~53%; Summary of findings:; SFA, MUFA, PUFA, and cholesterol intake was not significantly associated with odds of incident MI. | Exposures:; - SFA (tertile); - MUFA (tertile); - PUFA (tertile); - Cholesterol (tertile); [underlined: Assessment method and timing]:; - Self-administered, validated semi-quantitative FFQ; - Assessed at baseline; Outcomes and assessment methods:; - Assessed during 5y of follow-up; - [underlined: Incident MI]: self-reported and confirmed by family physician, discharge hospital records; - [underlined: Incident MI]: 108 cases | [underlined: Incident MI], OR, 95% CI; SFA:; T1 (ref) vs T2, T3: All NS, P=0.12; MUFA:; T1 (ref) vs T2, T3: All NS, P=0.57; PUFA:; T1 (ref) vs T2, T3: All NS, P=0.13; Cholesterol:; T1 (ref) vs T2, T3: All NS, P=0.20 | Key confounders [underlined: NOT] accounted for:; SES, Race/ethnicity, alcohol intake, physical activity, family history of CVD or diabetes; Key confounders accounted for:; Sex, age, TEI, smoking; Additional model adjustments:; BMI, hypertension; Limitations:; - Not all key confounders adjusted for; - Exposure was not quantified; - No information on missing data; - No preregistered statistical analyis plan; Funding sources:; Italian National Institute of Health
Neelakantan, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/27306893) ^189^; NCC, SCHS (Singapore Chinese Health Study), Singapore; Baseline N=63,257, Cases N=751, Matched Controls N=1443 (From subset who provided blood samples, N=NR); Participant characteristics at baseline:; - Singapore Chinese 45-74y of age without CAD or stroke at baseline.; - Matched on age, sex, dialect group, recruitment date, blood collection date; - Age: ~59y; - Sex (female): ~35%; - Race/ethnicity: 100% ethnic Chinese; - SES: Education >Secondary Level ~27%; - Anthropometry: BMI ~23; Fat intake at baseline, Mean (SD), Case vs Control:; - PUFA AHEI-2010 component score: 4.9 (1.8)vs 5.0 (1.8); - Long chain (n-3) PUFA AHEI-2010 component score: 8.4 (2.5) vs 8.7 (2.2); Blood lipids and BP at baseline, Mean (SD), Cases vs Controls:; - LDL (mmol/L): 3.3 (0.9) vs 3.2 (0.8); - HDL (mmol/L): 1.3 (0.3) vs 1.3 (0.3); - SBP (mmHg): 149 (24) vs 140 (22); - DBP (mmHg): 83 (14) vs 81 (10); Summary of findings:; Higher intake scores on the AHEI-2010 for long chain (n-3) PUFA, but not total PUFA, at ~59y of age was significantly associated with lower odds of acute myocardial infarction over ~17y of follow-up. | Exposures:; - PUFA (continuous; per 2 point increase in AHEI-2010 component score; - Criteria for minimum score (0): ≤2%E; - Criteria for maximum score (10): ≥10%E; - Long-chain (n-3) PUFA (continuous; per 2 point increase in AHEI-2010 component score; - Criteria for minimum score (0): 0 mg/d; - Criteria for maximum score (10): 250 mg/d; [underlined: Assessment method and timina]:; - Validated, semi-quantitative, 165-item FFQ assessing intake during the previous year; - Assessed at baseline; Outcomes and assessment methods:; - Assessed up to ~17y of follow-up; - Incident Acute MI (fatal and nonfatal): Obtained through linkage with national Mediclaim System Hospital Discharge Database, Singapore Myocardial Infarction Registry, and Singapore Registry of Births and Deaths; - Total: 751 cases (288 fatal, 564 nonfatal) | PUFA; [underlined: Total Acute MI], OR (95% CI); 0.90 (0.81, 1.00), P=0.07; Long-chain (n-3) PUFA; [underlined: Total Acute MI], OR (95% CI); 0.85 (0.78, 0.93), P<0.001 | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes; Key confounders accounted for:; Sex, age, race/ethnicity, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments:; Father’s dialect, year of birth, year of recruitment, BMI, history of diabetes, history of hypertension; Limitations:; - Not all key confounders accounted for; - No information on whether those who did not provide blood samples (and were excluded from analyses) differed from those who provided blood samples (and were included); - No preregistered statistical analysis plan; Funding sources:; NCI; National Medical Research Council, Singapore
Sun, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/26609174) ^209^; NCC, SCHS (Singapore Chinese Health Study), Singapore; Baseline N=63,257, Cases N=744, Matched Controls N=744 (From subset who provided blood samples, N=NR); Participant characteristics at baseline:; - Singapore Chinese 45-74y of age without cancer, CAD, or stroke at baseline.; - Matched on age, sex, dialect group, recruitment date, blood collection date; - Age: ~66y; - Sex (female): ~35%; - Race/ethnicity: 100% ethnic Chinese; - SES: Education >Secondary Level ~27%; - Anthropometry: BMI ~23; Fat intake at baseline:; - See “Exposures” in next column; Blood lipids, BP at baseline, Mean (SD):; - LDL (mmol/L): Cases, 3.3 (0.9); Controls, 3.2 (0.8); - HDL (mmol/L): Cases, 1.3 (0.3); Controls, 1.4 (0.3); - Hypertension: 46.9% cases, 36.8% controls; Summary of findings:; EPA+DHA intake at ~66y of age was significantly associated with lower odds of total, fatal, and nonfatal acute myocardial infarction in this nested case-control study. ALA intake at baseline was not significantly associated with total, fatal, or nonfatal acute myocardial infarction. | Exposures:; - ALA (quartiles; %E), Median; - Q1 (ref): 0.21 %E; - Q2: 0.27%E; - Q3: 0.32%E; - Q4: 0.41%E; - EPA+DHA (quartiles; %E), Median; - Q1 (ref): 0.09%E; - Q2: 0.15%E; - Q3: 0.20%E; - Q4: 0.29%E; [underlined: Assessment method and timing:]; - Validated, semi-quantitative, 165-item FFQ assessing intake during the previous year; - Assessed at baseline; Outcomes and assessment methods:; - Assessed up to ~17y of follow-up; - Incident Acute MI (fatal and nonfatal): Obtained through linkage with national Mediclaim System Hospital Discharge Database, Singapore Myocardial Infarction Registry, and Singapore Registry of Births and Deaths; - Fatal: 289; - Nonfatal: 555 | ALA; [underlined: Total Acute MI], OR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend: 0.87; [underlined: Fatal Acute MI], OR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend: 0.45; [underlined: Nonfatal Acute MI], HR (95% CI); Q1 (ref) vs Q2, Q3, or Q4: All NS; P-trend: 0.86; EPA+DHA; [underlined: Total Acute MI], OR (95% CI); Q1 (ref) vs Q2: 0.64 (0.46, 0.88); Q1 (ref) vs Q3: 0.73 (0.53, 0.99); Q1 (ref) vs Q4: 0.64 (0.46, 0.89); P-trend: 0.03; [underlined: Fatal Acute MI], OR (95% CI); Q1 (ref) vs Q2: 0.67 (0.38, 1.19); Q1 (ref) vs Q3: 0.59 (0.35, 0.99); Q1 (ref) vs Q4: 0.46 (0.26, 0.80); P-trend: 0.006; [underlined: Nonfatal Acute MI], OR (95% CI); Q1 (ref) vs Q2: 0.57 (0.39, 0.83); Q1 (ref) vs Q3: 0.68 (0.48, 0.98); Q1 (ref) vs Q4: 0.66 (0.45, 0.97); P-trend: 0.12 | Key confounders [underlined: NOT] accounted for:; Family history of CVD or diabetes; Key confounders accounted for:; Sex, age, race/ethnicity, SES (education), TEI, smoking, alcohol intake, physical activity.; Additional model adjustments:; Father’s dialect, year of birth, year of recruitment, BMI, cholesterol intake, fiber intake, total fat intake, history of hypertension and diabetes; Limitations:; - Not all key confounders accounted for; - Did not account for co-exposures (other fatty acids); - No information on whether those who did not provide blood samples (and were excluded from analyses) differed from those who provided blood samples (and were included); - No preregistered statistical analysis plan; Funding sources:; NIH; National Medical Research Council, Singapore

* Abbreviations: AHEI – Alternative Healthy Eating Index, BP – blood pressure, d – day(s), DBP – diastolic blood pressure, HDL – HDL cholesterol, HF – heart failure, LDL – LDL cholesterol, NR – not reported, NS – non significant, OR – odds ratio, %E – percent energy, ref – reference group, SD – standard deviation, SBP – systolic blood pressure, SES – socioeconomic status, TEI – total energy intake, y – year

† Statistically significant results bolded.

Table 10 Risk of bias for observational studies examining types of dietary fat consumed by adults and cardiovascular disease endpoint outcomes^*,,†^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Abdollahi, 2019,^135^ PCS | Serious | Low | Moderate | Low | Low | Low | Moderate
Akbaraly, 2011,^136^ PCS | Serious | Low | Moderate | Moderate | Moderate | Low | Moderate
Akesson, 2019,^137^ PCS | Serious | Moderate | Low | Low | Low | Low | Moderate
Amiano, 2014,^138^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Atkinson, 2011,^139^ PCS | Serious | Low | Moderate | Moderate | Low | Low | Moderate
Belin, 2011,^140^ PCS | Serious | Low | Low | Moderate | Moderate | Low | Moderate
Belin, 2011a,^141^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Bell, 2014,^142^ PCS | Moderate | Low | Moderate | Moderate | Moderate | Low | Moderate
Bendinelli, 2011,^143^ PCS | Serious | Moderate | Low | Low | Low | Low | Moderate
Bergkvist, 2014,^146^ PCS | Serious | Low | Low | Moderate | Low | Low | Moderate
Bergkvist, 2015,^145^ PCS | Serious | Moderate | Low | Low | Low | Low | Moderate
Bergkvist, 2016,^144^ sPCS | Serious | Moderate | Low | Moderate | Low | Low | Moderate
Blekkenhorst, 2015,^147^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Bork, 2016,^148^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Bork, 2018,^149^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Buckland, 2012,^150^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Buckland, 2012a,^151^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Chiuve, 2012,^152^ PCS | Serious | Low | Low | Low | Moderate | Low | Moderate
de Goede, 2010,^153^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
de Goede, 2011,^155^ PCS | Serious | Moderate | Low | Low | Low | Low | Moderate
de Goede, 2012,^154^ PCS | Serious | Moderate | Low | Low | Low | Low | Moderate
de Oliveira Otto, 2012,^156^ PCS | Serious | Moderate | Low | Low | Low | Low | Moderate
de Oliveira Otto, 2013,^157^ PCS | Serious | Low | Low | Moderate | Low | Low | Moderate
Donat-Vargas, 2019,^158^ PCS | Serious | Moderate | Low | Moderate | Low | Low | Moderate
Fretts, 2014,^159^ PCS | Serious | Low | Low | Moderate | Moderate | Low | Moderate
Gammelmark, 2016,^160^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Gardener, 2011,^161^ PCS | Serious | Low | Low | Moderate | Moderate | Low | Moderate
Goldbohm, 2011,^162^ PCS | Serious | Low | Moderate | Low | Moderate | Low | Moderate
Guasch-Ferre, 2014,^164^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Guasch-Ferre, 2015,^163^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Hellstrand, 2014,^165^ PCS | Serious | Moderate | Moderate | Moderate | Low | Low | Moderate
Hisamatsu, 2013,^166^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Hlebowicz, 2013,^167^ PCS | Serious | Moderate | Low | Moderate | Low | Low | Moderate
Houston, 2011,^168^ PCS | Serious | Low | Moderate | Low | Moderate | Low | Moderate
Isaksen, 2019,^169^ PCS | Serious | Low | Moderate | Moderate | Moderate | Low | Moderate
Jakobsen, 2010,^170^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Joensen, 2010,^171^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Juan, 2018,^172^ NCC | Serious | Low | Low | Moderate | No information | Low | Moderate
Kiage, 2015,^173^ PCS | Serious | No information | Low | Low | No information | Low | Moderate
Kippler, 2016,^174^ PCS | Serious | Low | Low | Moderate | Low | Low | Moderate
Koh, 2015,^175^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Koskinen, 2018,^176^ PCS | Serious | Low | Moderate | Low | Low | Low | Moderate
Kouli, 2019,^177^ PCS | Serious | Low | Low | Low | Moderate | Low | Moderate
Kulezic, 2019,^178^ PCS | Serious | Moderate | Low | Low | Low | Low | Moderate
Larsson, 2012,^179^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Lemaitre, 2012,^180^ PCS | Serious | Low | Low | Moderate | Low | Low | Moderate
Levitan, 2010,^182^ PCS | Serious | Moderate | Low | Low | Low | Low | Moderate
Levitan, 2012,^181^ PCS | Serious | Moderate | Low | Moderate | Low | Low | Moderate
Li, 2015,^183^ PCS | Serious | Moderate | Low | Moderate | Moderate | Low | Moderate
Lin, 2018,^184^ PCS | Serious | Moderate | Moderate | Moderate | Moderate | No information | Moderate
Miyagawa, 2014,^185^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Nagata, 2012,^186^ PCS | Serious | Moderate | Low | Low | Low | Low | Moderate
Nakamura, 2013,^187^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Neelakantan, 2016,^189^ NCC | Serious | Low | Low | Low | Moderate | Low | Moderate
Neelakantan, 2018,^188^ PCS | Serious | Low | Moderate | Low | Low | Low | Moderate
Okada, 2019,^190^ PCS | Serious | Low | Serious | Low | Low | Low | Moderate
O’Neil, 2015,^191^ PCS | Serious | Low | Moderate | Moderate | Low | Low | Moderate
Owen, 2016,^192^ PCS | Serious | Low | Low | Moderate | Low | Low | Moderate
Pala, 2019,^193^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Patterson, 2013,^194^ PCS | Serious | Moderate | Moderate | Low | Low | Low | Moderate
Pierucci, 2012,^195^ NCC | Serious | Low | Moderate | Low | Moderate | Low | Moderate
Praagman, 2016,^196^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Praagman, 2016a,^197^ PCS | Serious | Moderate | Low | Low | Low | Low | Moderate
Praagman, 2019,^198^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Reedy, 2014,^199^ PCS | Serious | Low | Low | Moderate | Low | Low | Moderate
Rhee, 2017,^200^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Ricci, 2018,^201^ PCS | Serious | Moderate | Low | Low | Moderate | Low | Moderate
Sala-Vila, 2016,^202^ PCS | Serious | Low | Low | Moderate | Low | Low | Moderate
Samieri, 2011,^203^ PCS | Serious | Low | Moderate | Low | Moderate | Low | Moderate
Santiago, 2018,^204^ PCS | Serious | Low | Low | Moderate | Low | Low | Moderate
Simila, 2013,^205^ PCS | Serious | Moderate | Low | Low | Low | Low | Moderate
Sonestedt, 2011,^206^ PCS | Serious | Moderate | Low | Moderate | Low | Low | Moderate
Stefler, 2017,^207^ PCS | Serious | Moderate | Moderate | Low | Low | Low | Moderate
Strom, 2012,^208^ PCS | Serious | Moderate | Low | Low | Low | Low | Moderate
Sun, 2016,^209^ NCC | Serious | Low | Low | Moderate | Moderate | Low | Moderate
Vedtofte, 2011,^210^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Veno, 2017,^212^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Veno, 2019,^211^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Virtanen, 2014,^213^ PCS | Serious | Low | Moderate | Low | Low | Low | Moderate
Virtanen, 2016,^214^ PCS | Serious | Low | Moderate | Low | Low | Low | Moderate
Vissers, 2019,^215^ PCS | Serious | Low | Low | Low | Moderate | Low | Moderate
Wakai, 2014,^216^ PCS | Serious | Low | Low | Moderate | Moderate | Low | Moderate
Wallstrom, 2012,^217^ PCS | Serious | Moderate | Low | Moderate | Low | Low | Moderate
Wang, 2016,^218^ PCS | Moderate | Moderate | Low | Low | Low | Low | Moderate
Wilk, 2012,^219^ PCS | Serious | Low | Low | Moderate | Low | Low | Moderate
Yaemsiri, 2012,^220^ PCS | Serious | Low | Low | Moderate | Low | Low | Moderate
Yamagishi, 2010,^222^ PCS | Serious | Low | Moderate | Low | Moderate | Low | Moderate
Yamagishi, 2013,^221^ PCS | Serious | Low | Moderate | Low | Low | Low | Moderate
Zhang, 2018,^223^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Zhong, 2019,^224^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Zhuang, 2019,^225^ PCS | Moderate | Low | Moderate | Low | Low | Low | Moderate
Zhuang, 2019a,^226^ PCS | Serious | Low | Low | Low | Low | Low | Moderate
Zong, 2016,^228^ PCS | Serious | Moderate | Low | Moderate | Low | Low | Moderate
Zong, 2018,^227^ PCS | Serious | Moderate | Low | Moderate | Moderate | Low | Moderate

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

v Dietary Guidelines Advisory Committee. 2015. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. U.S. Department of Agriculture, Agricultural Research Service, Washington, D.C.

vi Dietary Guidelines Advisory Committee. 2015. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. U.S. Department of Agriculture, Agricultural Research Service, Washington, D.C.

vii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

viii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

ix Dietary Guidelines Advisory Committee. 2015. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. U.S. Department of Agriculture, Agricultural Research Service, Washington, D.C.

x A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xi Dietary Guidelines Advisory Committee. 2015. Scientific Report of the 2015 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and the Secretary of Agriculture. U.S. Department of Agriculture, Agricultural Research Service, Washington, D.C.