# References of the articles included in the systematic review

1 Aerts GS, T. The package size effect: How package size affects young children’s consumption of snacks differing in sweetness. Food Qual Prefer. 2017;60:8. doi:10.1016/j.foodqual.2017.03.015
2 Keller KL, Pearce AL, Fuchs B, . Children with lower ratings of executive functions have a greater response to the portion size effect. Appetite. Jul 1 2023;186:106569. doi:10.1016/j.appet.2023.106569 37059397
3 Diktas HE, Keller KL, Roe LS, Rolls BJ. Children’s Portion Selection Is Predicted by Food Liking and Is Related to Intake in Response to Increased Portions. J Nutr. Oct 6 2022;152(10):2287–2296. doi:10.1093/jn/nxac162 35883226
4 Huss LR, Laurentz S, Fisher JO, McCabe GP, Kranz S. Timing of serving dessert but not portion size affects young children’s intake at lunchtime. Appetite. Sep 2013;68:158–63. doi:10.1016/j.appet.2013.04.013 23619315
5 Roe LS, Sanchez CE, Smethers AD, Keller KL, Rolls BJ. Portion size can be used strategically to increase intake of vegetables and fruits in young children over multiple days: a cluster-randomized crossover trial. Am J Clin Nutr. Jan 11 2022;115(1):272–283. doi:10.1093/ajcn/nqab321 34550306
6 Diktas HE, Roe LS, Keller KL, Sanchez CE, Rolls BJ. Promoting vegetable intake in preschool children: Independent and combined effects of portion size and flavor enhancement. Appetite. Sep 1 2021;164:105250. doi:10.1016/j.appet.2021.105250 33836215
7 Smethers AD, Roe LS, Sanchez CE, . Portion size has sustained effects over 5 days in preschool children: a randomized trial. Am J Clin Nutr. May 1 2019;109(5):1361–1372. doi:10.1093/ajcn/nqy383 30976782
8 Carstairs SA, Caton SJ, Blundell-Birtill P, Rolls BJ, Hetherington MM, Cecil JE. Can Reduced Intake Associated with Downsizing a High Energy Dense Meal Item be Offset by Increased Vegetable Variety in 3(-)5-year-old Children? Nutrients. Dec 3 2018;10(12)doi:10.3390/nu10121879
9 Kling SM, Roe LS, Sanchez CE, Rolls BJ. Does milk matter: Is children’s intake affected by the type or amount of milk served at a meal? Appetite. Oct 1 2016;105:509–18. doi:10.1016/j.appet.2016.06.022 27338218
10 Kling SM, Roe LS, Keller KL, Rolls BJ. Double trouble: Portion size and energy density combine to increase preschool children’s lunch intake. Physiol Behav. Aug 1 2016;162:18–26. doi:10.1016/j.physbeh.2016.02.019 26879105
11 Norton EM, Poole SA, Raynor HA. Impact of fruit juice and beverage portion size on snack intake in preschoolers. Appetite. Dec 2015;95:334–40. doi:10.1016/j.appet.2015.07.025 26232137
12 Mooreville M, Davey A, Orloski A, . Individual differences in susceptibility to large portion sizes among obese and normal-weight children. Obesity (Silver Spring). Apr 2015;23(4):808–14. doi:10.1002/oby.21014 25683105
13 Kral TV, Remiker AM, Strutz EM, Moore RH. Role of child weight status and the relative reinforcing value of food in children’s response to portion size increases. Obesity (Silver Spring). Jul 2014;22(7):1716–22. doi:10.1002/oby.20757 24733645
14 Fisher JO, Birch LL, Zhang J, Grusak MA, Hughes SO. External influences on children’s self-served portions at meals. Int J Obes (Lond). Jul 2013;37(7):954–60. doi:10.1038/ijo.2012.216 23295501
15 Mathias KC, Rolls BJ, Birch LL, . Serving larger portions of fruits and vegetables together at dinner promotes intake of both foods among young children. J Acad Nutr Diet. Feb 2012;112(2):266–70. doi:10.1016/j.jada.2011.08.040 22741168
16 Savage JS, Fisher JO, Marini M, Birch LL. Serving smaller age-appropriate entree portions to children aged 3-5 y increases fruit and vegetable intake and reduces energy density and energy intake at lunch. Am J Clin Nutr. Feb 2012;95(2):335–41. doi:10.3945/ajcn.111.017848 22205315
17 Spill MK, Birch LL, Roe LS, Rolls BJ. Serving large portions of vegetable soup at the start of a meal affected children’s energy and vegetable intake. Appetite. Aug 2011;57(1):213–9. doi:10.1016/j.appet.2011.04.024 21596073
18 Looney SM, Raynor HA. Impact of portion size and energy density on snack intake in preschool-aged children. J Am Diet Assoc. Mar 2011;111(3):414–8. doi:10.1016/j.jada.2010.11.016 21338741
19 Spill MK, Birch LL, Roe LS, Rolls BJ. Eating vegetables first: the use of portion size to increase vegetable intake in preschool children. Am J Clin Nutr. May 2010;91(5):1237–43. doi:10.3945/ajcn.2009.29139 20219955
20 Kral TV, Kabay AC, Roe LS, Rolls BJ. Effects of doubling the portion size of fruit and vegetable side dishes on children’s intake at a meal. Obesity (Silver Spring). Mar 2010;18(3):521–7. doi:10.1038/oby.2009.243 19680238
21 Fisher JO, Arreola A, Birch LL, Rolls BJ. Portion size effects on daily energy intake in low-income Hispanic and African American children and their mothers. Am J Clin Nutr. Dec 2007;86(6):1709–16. doi:10.1093/ajcn/86.5.1709 18065590
22 Fisher JO, Liu Y, Birch LL, Rolls BJ. Effects of portion size and energy density on young children’s intake at a meal. Am J Clin Nutr. Jul 2007;86(1):174–9. doi:10.1093/ajcn/86.1.174 17616778
23 Fisher JO. Effects of age on children’s intake of large and self-selected food portions. Obesity (Silver Spring). Feb 2007;15(2):403–12. doi:10.1038/oby.2007.549 17299114
24 Orlet Fisher J, Rolls BJ, Birch LL. Children’s bite size and intake of an entree are greater with large portions than with age-appropriate or self-selected portions. Am J Clin Nutr. May 2003;77(5):1164–70. doi:10.1093/ajcn/77.5.1164 12716667
25 Rolls BJ, Engell D, Birch LL. Serving portion size influences 5-year-old but not 3-year-old children’s food intakes. J Am Diet Assoc. Feb 2000;100(2):232–4. doi:10.1016/S0002-8223(00)00070-5 10670398
26 Reale S, Kearney CM, Hetherington MM, . The Feasibility and Acceptability of Two Methods of Snack Portion Control in United Kingdom (UK) Preschool Children: Reduction and Replacement. Nutrients. Oct 12 2018;10(10). doi:10.3390/nu10101493
27 McCrickerd K, Leong C, Forde CG. Preschool children’s sensitivity to teacher-served portion size is linked to age related differences in leftovers. Appetite. Jul 1 2017;114:320–328. doi:10.1016/j.appet.2017.04.003 28389138
28 Marchiori D, Waroquier L, Klein O. “Split them!” smaller item sizes of cookies lead to a decrease in energy intake in children. J Nutr Educ Behav. May-Jun 2012;44(3):251–5. doi:10.1016/j.jneb.2011.07.007 22391143
29 Haynes A, Hardman CA, Halford JCG, Jebb SA, Robinson E. Portion size normality and additional within-meal food intake: two crossover laboratory experiments. Br J Nutr. Feb 28 2020;123(4):462–471. doi:10.1017/S0007114519002307 31488225
30 Gough T, Haynes A, Clarke K, . Out of the lab and into the wild: The influence of portion size on food intake in laboratory vs. real-world settings. Appetite. Jul 1 2021;162:105160. doi:10.1016/j.appet.2021.105160 33556391
31 Cunningham PM, Roe LS, Keller KL, Rolls BJ. Variety and portion size combine to increase food intake at single-course and multi-course meals. Appetite. Dec 1 2023;191. doi:ARTN 10.1016/j.appet.2023.107089
32 Robinson E, Kersbergen I. Portion size and later food intake: evidence on the “normalizing” effect of reducing food portion sizes. Am J Clin Nutr. Apr 1 2018;107(4):640–646. doi:10.1093/ajcn/nqy013 29635503
33 Rolls BJ, Roe LS, Meengs JS. Portion size can be used strategically to increase vegetable consumption in adults. Am J Clin Nutr. Apr 2010;91(4):913–22.20147467
34 Berkowitz S, Marquart L, Mykerezi E, Degeneffe D, Reicks M. Reduced-portion entrées in a worksite and restaurant setting: impact on food consumption and waste. Public Health Nutr. Nov 2016;19(16):3048–3054.27256403
35 Langfield T, Clarke K, Marty L, Jones A, Robinson E. Socioeconomic position and the influence of food portion size on daily energy intake in adult females: two randomized controlled trials. Int J Behav Nutr Phys Act. Apr 27 2023;20(1):53. doi:10.1186/s12966-023-01453-x 37101143
36 Rolls BJ, Roe LS, Meengs JS, Wall DE. Increasing the portion size of a sandwich increases energy intake. J Am Diet Assoc. Mar 2004;104(3):367–72. doi:10.1016/j.jada.2003.12.013 14993858
37 Cunningham PM, Roe LS, Keller KL, Rolls BJ. Switching between bites of food and sips of water is related to food intake across meals varying in portion size. Appetite. Mar 1 2023;182:106443. doi:10.1016/j.appet.2022.106443 36581110
38 Cahayadi J, Geng X, Mirosa M, Peng M. Expectancy versus experience - Comparing Portion-Size-Effect during pre-meal planning and actual intake. Appetite. Apr 1 2019;135:108–114. doi:https://doi.org/10.1016/j.appet.2019.01.012 30639843
39 Zuraikat FM, Roe LS, Privitera GJ, Rolls BJ. Increasing the size of portion options affects intake but not portion selection at a meal. Appetite. Mar 1 2016;98:95–100. doi:10.1016/j.appet.2015.12.023 26721718
40 Almiron-Roig E, Tsiountsioura M, Lewis HB, Wu J, Solis-Trapala I, Jebb SA. Large portion sizes increase bite size and eating rate in overweight women. Physiol Behav. Feb 2015;139:297–302. doi:10.1016/j.physbeh.2014.11.041 25449410
41 Rolls BJ, Morris EL, Roe LS. Portion size of food affects energy intake in normal-weight and overweight men and women. Am J Clin Nutr. Dec 2002;76(6):1207–13. doi:10.1093/ajcn/76.6.1207 12450884
42 Rosenthal R, Raynor H. The effect of television watching and portion size on intake during a meal. Appetite. Oct 1 2017;117:191–196. doi:10.1016/j.appet.2017.06.030 28673808
43 Roe LS, Kling SMR, Rolls BJ. What is eaten when all of the foods at a meal are served in large portions? Appetite. Apr 1 2016;99:1–9. doi:10.1016/j.appet.2016.01.001 26767612
44 Levitsky DA, Youn T. The more food young adults are served, the more they overeat. J Nutr. Oct 2004;134(10):2546–9. doi:10.1093/jn/134.10.2546 15465745
45 Zuraikat FM, Roe LS, Smethers AD, Rolls BJ. Doggy bags and downsizing: Packaging uneaten food to go after a meal attenuates the portion size effect in women. Appetite. Oct 1 2018;129:162–170. doi:10.1016/j.appet.2018.07.009 29990524
46 Zuraikat FM, Roe LS, Sanchez CE, Rolls BJ. Comparing the portion size effect in women with and without extended training in portion control: A follow-up to the Portion-Control Strategies Trial. Appetite. Apr 1 2018;123:334–342. doi:10.1016/j.appet.2018.01.012 29353006
47 Long JW, Pritschet SJ, Keller KL, . Portion size affects food selection in an immersive virtual reality buffet and is related to measured intake in laboratory meals varying in portion size. Appetite. Dec 1 2023;191doi:ARTN 107052 10.1016/j.appet.2023.107052
48 Jeffery RW, Rydell S, Dunn CL, . Effects of portion size on chronic energy intake. Int J Behav Nutr Phys Act. Jun 27 2007;4:27. doi:10.1186/1479-5868-4-27 17597516
49 Rolls BJ, Roe LS, Meengs JS. Larger portion sizes lead to a sustained increase in energy intake over 2 days. J Am Diet Assoc. Apr 2006;106(4):543–9. doi:10.1016/j.jada.2006.01.014 16567150
50 Rolls BJ, Roe LS, Meengs JS. Reductions in portion size and energy density of foods are additive and lead to sustained decreases in energy intake. Am J Clin Nutr. Jan 2006;83(1):11–7. doi:10.1093/ajcn/83.1.11 16400043
51 Kelly MT, Wallace JM, Robson PJ, . Increased portion size leads to a sustained increase in energy intake over 4 d in normal-weight and overweight men and women. Br J Nutr. Aug 2009;102(3):470–7. doi:10.1017/S0007114508201960 19216813
52 Rolls BJ, Roe LS, Meengs JS. The effect of large portion sizes on energy intake is sustained for 11 days. Obesity (Silver Spring). Jun 2007;15(6):1535–43. doi:10.1038/oby.2007.182 17557991
53 Levitsky D, Agaronnik N, Zhong W, Morace C, Barre L, Michael JJ. Reducing an entree portion size does not affect the amount of dessert consumed. Appetite. Aug 1 2020;151:104684. doi:10.1016/j.appet.2020.104684 32234533
54 Rolls BJ, Roe LS, Meengs JS. Salad and satiety: energy density and portion size of a first-course salad affect energy intake at lunch. J Am Diet Assoc. Oct 2004;104(10):1570–6. doi:10.1016/j.jada.2004.07.001 15389416
55 Williams RA, Roe LS, Rolls BJ. Assessment of satiety depends on the energy density and portion size of the test meal. Obesity (Silver Spring). Feb 2014;22(2):318–24. doi:10.1002/oby.20589 23929544
56 Shimpo M, Akamatsu R. The effects of bowl size and portion size on food intake and fullness ratings in a sample of Japanese men. Public Health Nutr. Dec 2018;21(17):3216–3222. doi:10.1017/S1368980018001842 30079861
57 Rolls BJ, Roe LS, Kral TV, Meengs JS, Wall DE. Increasing the portion size of a packaged snack increases energy intake in men and women. Appetite. Feb 2004;42(1):63–9. doi:10.1016/S0195-6663(03)00117-X 15036784
58 Flood JE, Roe LS, Rolls BJ. The effect of increased beverage portion size on energy intake at a meal. J Am Diet Assoc. Dec 2006;106(12):1984–90; discussion 1990-1. doi:10.1016/j.jada.2006.09.005 17126628
59 Zuraikat FM, Roe LS, Smethers AD, Reihart LW, Rolls BJ. Does the cost of a meal influence the portion size effect? Appetite. Aug 1 2018;127:341–348. doi:10.1016/j.appet.2018.05.020 29772292
60 Ziylan C, Kremer S, Eerens J, Haveman-Nies A, de Groot LC. Effect of meal size reduction and protein enrichment on intake and satiety in vital community-dwelling older adults. Appetite. Oct 1 2016;105:242–8. doi:10.1016/j.appet.2016.05.032 27238898
61 Lewis HB, Ahern AL, Solis-Trapala I, . Effect of reducing portion size at a compulsory meal on later energy intake, gut hormones, and appetite in overweight adults. Obesity (Silver Spring). Jul 2015;23(7):1362–70. doi:10.1002/oby.21105 26054049
62 Burger KS, Fisher JO, Johnson SL. Mechanisms behind the portion size effect: visibility and bite size. Obesity (Silver Spring). Mar 2011;19(3):546–51. doi:doi.org/10.1038/oby.2010.233 20948520
63 Kral TV, Roe LS, Rolls BJ. Combined effects of energy density and portion size on energy intake in women. Am J Clin Nutr. Jun 2004;79(6):962–8. doi:10.1093/ajcn/79.6.962 15159224
64 Haynes A, Hardman CA, Halford JCG, Jebb SA, Mead BR, Robinson E. Reductions to main meal portion sizes reduce daily energy intake regardless of perceived normality of portion size: a 5 day cross-over laboratory experiment. Int J Behav Nutr Phys Act. Feb 12 2020;17(1):21. doi:10.1186/s12966-020-0920-4 32050979
65 Ellahi B, Aitken A, Dikmen D, Seyhan-Erdogan B, Makda M, Razaq R. Acceptability, Usability and Weight Loss Outcomes in a Randomized Cross-Over Study of Commercially Available Portion Size Tools in an Overweight South Asian Community. Int J Environ Res Public Health. Jun 23 2022;19(13)doi:10.3390/ijerph19137714
66 Robinson E, te Raa W, Hardman CA. Portion size and intended consumption. Evidence for a pre-consumption portion size effect in males? Appetite. Aug 2015;91:83–9. doi:10.1016/j.appet.2015.04.009 25865660
67 Marchiori D, Papies EK. A brief mindfulness intervention reduces unhealthy eating when hungry, but not the portion size effect. Appetite. Apr 2014;75:40–5. doi:10.1016/j.appet.2013.12.009 24361312
68 Reily NM, Vartanian LR. The portion size effect on food intake is robust to contextual size information. Appetite. Oct 1 2016;105:439–48. doi:10.1016/j.appet.2016.06.015 27311378
69 Raghoebar S, Haynes A, Robinson E, Kleef EV, Vet E. Served Portion Sizes Affect Later Food Intake Through Social Consumption Norms. Nutrients. Nov 20 2019;11(12)doi:10.3390/nu11122845
70 Diliberti N, Bordi PL, Conklin MT, Roe LS, Rolls BJ. Increased portion size leads to increased energy intake in a restaurant meal. Obes Res. Mar 2004;12(3):562–8. doi:10.1038/oby.2004.64 15044675
71 French SA, Mitchell NR, Wolfson J, . Portion size effects on weight gain in a free living setting. Obesity (Silver Spring). Jun 2014;22(6):1400–5. doi:10.1002/oby.20720 24510841
72 Haire C, Raynor HA. Weight status moderates the relationship between package size and food intake. J Acad Nutr Diet. Aug 2014;114(8):1251–6. doi:10.1016/j.jand.2013.12.022 24556428
73 Raynor HA, Van Walleghen EL, Niemeier H, Butryn ML, Wing RR. Do food provisions packaged in single-servings reduce energy intake at breakfast during a brief behavioral weight-loss intervention? Journal of the American Dietetic Association. 2009;109(11):1922–1925.19857636
74 Reister EJ, Leidy HJ. Snack Package Size and Variety Differentially Influence Energy Intake and Food Choices in Healthy Adults. Curr Dev Nutr. Feb 2022;6(2):nzac004. doi:10.1093/cdn/nzac004 35155984
75 Rolls BJ, Roe LS, James BL, Sanchez CE. Does the incorporation of portion-control strategies in a behavioral program improve weight loss in a 1-year randomized controlled trial? Int J Obes (Lond). Mar 2017;41(3):434–442. doi:10.1038/ijo.2016.217 27899807
76 Devitt AA, Mattes RD. Effects of food unit size and energy density on intake in humans. Appetite. Apr 2004;42(2):213–20. doi:10.1016/j.appet.2003.10.003 15010185
77 Raynor HA, Wing RR. Package unit size and amount of food: do both influence intake? Obesity (Silver Spring). Sep 2007;15(9):2311–9. doi:10.1038/oby.2007.274 17890500
78 van Kleef E, Kavvouris C, van Trijp HCM. The unit size effect of indulgent food: How eating smaller sized items signals impulsivity and makes consumers eat less. Psychology & Health. 2014;29(9):1081–1103.24678943