# Summary of conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee answered the systematic review question, “What is the relationship between portion size and energy intake?”, with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Young children, children, and adolescents

Serving larger portions of energy dense foods increases energy intake in children. This conclusion statement is based on evidence graded as strong. (Grade: Strong)

Serving larger portions of vegetables and fruits increases intake of those foods without increasing energy intake in children. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

A conclusion statement cannot be drawn about the relationship between portion size and energy intake in young children and adolescents because there is no evidence available. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between pre-portioned foods by young children, children, and adolescents and energy intake because there is not enough evidence available. (Grade: Grade Not Assignable)

### Adults and older adults

Serving larger portions of foods increases food and energy intake in adults and older adults. This conclusion statement is based on evidence graded as strong. (Grade: Strong)

Portion size and energy density are independent and additive in their effects on energy intake in adults and older adults. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

Serving foods as smaller pre-portioned amounts decreases energy intake in adults and older adults. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

### Individuals during pregnancy and postpartum

A conclusion statement cannot be drawn about the relationship between portion size and energy intake during pregnancy because there is no evidence available. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between pre-portioned foods and energy intake during pregnancy because there is no evidence available. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between portion size and energy intake during postpartum because there is no evidence available. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between pre-portioned foods and energy intake during postpartum because there is no evidence available. (Grade: Grade Not Assignable)

## Research recommendations

- Design and conduct portion size interventions of longer duration and in free-living settings, including the strategic use of portion size to better control total energy intake and improve diet quality. Examine how changing the portion size of some foods impacts intake of other foods served at a meal.
- Apply best practices for nutrition research by measuring and reporting adherence data and conducting adequately powered trials.
- Ensure adequate representation of populations in which evidence is lacking including young children, adolescents, individuals during pregnancy and postpartum, older adults, and among diverse populations (e.g., minoritized racial and/or ethnic groups, individuals of various socioeconomic positions, individuals of various geographical locations, individuals with various countries of birth and/or length of time in the U.S.)
- Include a variety of pre-portioned meal options such as commercially prepared products, researcher prepared meals, and meals prepared at home.
- Conduct research to determine the effects of portion control in the context of medically tailored meals (food is medicine).
- Conduct family-based studies that examine the intervention/exposures at the family level and assesses outcomes among all family members.

Table 15 Evidence examining the relationship between portion size and energy intake in young children, children, and adolescents^a^

Study and Population Characteristics | Intervention, Comparator, and Outcomes | Results | Confounding and Study Limitations
Fisher, 2007c^23^; RCT-crossover , U.S.; Baseline N=75,; Analytic N, Reference: N=65, Large: N=65,; Self-select: N=69 (Attrition: ~13%); Study objective: To study the effects of age on children’s responsiveness to large and self-selected portions; Participant characteristics at baseline: Children, 3 age groups: 2-3yrs, 5-6yrs, 8-9yrs; - [underlined: Age]: 2.6 (0.5) y; 5.6 (0.5) y; 8.7 (0.4) y; - [underlined: Female]: 41%; - [underlined: Race and/or ethnicity]: Non-Hispanic White: 100%; - [underlined: Socioeconomic position]: Parent education >high school: 93%; Employment: 51%; - [underlined: Anthropometry]: BMI percentile; 2-3y: 76 (33) % 5-6y: 61 (31) %; 8-9y: 75 (25) %; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Those not identifying as non-Hispanic White, presence of any chronic condition or medication affecting food intake, food allergies, BMI-for-age <5th percentile, dislike of 2 or more study foods. | Intervention:; [underlined: 2-3 year olds]; Condition 1: 100% (200g, 284kcal); Condition 2: 200% (400g, 568kcal); Condition 3: Self-selected individual serving dish, 200% (400g, 568kcal); [underlined: 5-6 year olds]; Condition 1: 100% (250g, 355kcal); Condition 2: 200% (500g, 710kal); Condition 3: Self-selected individual serving dish, 200% (500g, 710kcal); [underlined: 8-9 year olds]; Condition 1: 100% (450g, 639kcal); Condition 2: 200% (900g, 1278kcal); Condition 3: Self-selected individual serving dish, 200% (900g, 1278kcal); Duration: 1 meal (dinner) once a week for 3 weeks; Compliance: 8 excluded from reference condition, 2 from large condition, and 4 in the self-select condition for entree intake 0 grams. Two were excluded for change scores >3 SD above the mean.; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Energy intake, all children combined:; [underlined: Energy intake from the entree]: Condition 2 (200%) vs Condition 1 (100%): +29%, P<0.001; [underlined: Total energy intake from the meal]: Condition 2 (200%) vs Condition 1 (100%): +13%, P<0.001; Energy intake 2-3y children:; [underlined: Entree]: 100%= 133 (82) kcal; 200%= 145 (113) kcal; 200% self-serve= 127 (92) kcal; [underlined: Other foods]: 100%= 143 (80)kcal; 200%= 149 (59) kcal; 200% self-serve= 153 (68) kcal; [underlined: Total energy]: 100%= 276 (135) kcal; 200% =294 (123) kcal; 200% self-serve= 280 (134) kcal; Energy intake in 5-6y children:; [underlined: Entree]: 100%= 223 (83) kcal; 200%= 290 (145) kcal; 200% self-serve= 241 (156) kcal; [underlined: Other foods]: 100%= 257 (84) kcal; 200%= 271 (96) kcal; 200% self-serve= 260 (80) kcal; [underlined: Total energy]: 100%= 276 (85) kcal; 200% =294 (81) kcal; 200% self-serve= 261 (94) kcal; Energy intake in 8-9y children:; [underlined: Entree]: 100%= 361 (173) kcal; 200%= 407 (258) kcal; 200% self-serve= 380 (270) kcal; [underlined: Other foods]: 100%= 276 (85)kcal; 200%= 294 (81) kcal; 200% self-serve= 261 (94) kcal; [underlined: Total energy]: 100%= 637 (190) kcal; 200% =700 (282) kcal; 200% self-serve= 641 (286) kcal | Model adjustments: NA; Limitations:; - Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; North American International Life; Sciences Association Committee on; Lifestyle and Weight Management
Huss, 2013^4^; RCT-Crossover, U.S.; Baseline N=23, Analytic N=23 (Attrition: 0%); Study objective: To determine the individual and combined impact of the timing of serving dessert and portion size of main course on energy intake at lunch in a childcare setting; Participant characteristics at baseline: Children, 2-5, who attended full day childcare; - [underlined: Age]: 2-5 y; - [underlined: Female]: 26%; - [underlined: Race and/or ethnicity]: Caucasian: 56.5%; Asian: 30.4%; Other: 13.1%; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: NR; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Food restrictions, food allergies, or digestive diseases, such as Crohn’s Disease or Cystic Fibrosis | Intervention:; [underlined: Condition 1]: Reference portion (100%), dessert with lunch (~325 kcal, 2y; 400 kcal, 3-5y); [underlined: Condition 2]: Reference portion (100%), dessert after lunch (~325 kcal, 2y; 400 kcal, 3-5y); [underlined: Condition 3]: Large portion (150%), dessert with lunch (~490 kcal, 2y; 600 kcal, 3-5y); [underlined: Condition 4]: Large portion (150%), dessert after lunch (~490 kcal, 2y; 600 kcal, 3-5y); Duration: 1 meal (lunch), 2 times/week for 8 weeks; Compliance: NA; Outcomes and assessment methods: After meal; “Plate waste method,” not described | Energy intake from the main course, kcal (fish, pasta):; [underlined: Condition 1 (100%, dessert with lunch)]: 47 (32), 94 (65); [underlined: Condition 2 (100%, dessert after lunch)]: 62 (50), 91 (57); [underlined: Condition 3 (150%, dessert with lunch)]: 53 (36), 83 (68); [underlined: Condition 4 (150%), dessert after lunch)]: 57 (34), 100 (57); Portion size effect, P=NS; Energy intake from dessert, kcal (fish, pasta):; [underlined: Condition 1 (100%, dessert with lunch)]: 84 (38), 82 (37); [underlined: Condition 2 (100%, dessert after lunch)]: 97 (25), 87 (31); [underlined: Condition 3 (150%, dessert with lunch)]: 85 (36), 85 (35); [underlined: Condition 4 (150%), dessert after lunch)]: 88 (31), 87 (26); Portion size effect, P=NS; Total energy intake at lunch, kcal (fish, pasta):; [underlined: Condition 1 (100%, dessert with lunch)]: 131 (50), 176 (76); [underlined: Condition 2 (100%, dessert after lunch)]: 159 (58), 172 (65); [underlined: Condition 3 (150%, dessert with lunch)]: 138 (44), 166 (78); [underlined: Condition 4 (150%), dessert after lunch)]: 145 (40), 187 (67); Portion size effect, P=NS | Model adjustments: NA; Limitations:; - Randomization and concealment methods NR; Did not describe the outcome measurement, and concerns with mismeasurement; No preregistered data analysis plan; Funding: NR
Rolls, 2000^25^; RCT-crossover, U.S.; Baseline N=32, Analytic N=32 (Attrition: 0%); Study objective: To examine the effects of portion size on children’s food intake and to test the prediction that the effects of portion size on children’s food intake will be greater for 5 year old than 3 year old children; Participant characteristics at baseline: Preschool children, age 3-6y; - [underlined: Age]: 3.6y, 5y; - [underlined: Female]: 56%; - [underlined: Race and/or ethnicity]: White: 78%; African American: 6%; Asian: 6%; Other: 9%; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: Weight-for-height percentiles: 67.1 (3.4) % for 3y and 60.8 3.8) % for 5y; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: N; Excluded from study or analysis: NR | Intervention:; [underlined: 3y]; Condition 1: 100% entrée (150 g); Condition 2: 175% entrée (263 g); Condition 3: 250% entrée (376 g); [underlined: 5y]; Condition 1: 100% entrée (225 g); Condition 2: 150% entrée (338 g); Condition 3: 200% entrée (450 g); Duration: 1 meal (lunch) once a week for 3 weeks; Compliance: NR; Outcomes and assessment methods: Before and after test meal; Weighed food intake | Entree intake for 3y (g):; Condition 1 (100%): 44.8 (12.3) g; Condition 2 (175%): 54.6 (15.8) g; Condition 3 (250%): 39.6 (9.2) g; P=NS; Total meal intake for 3y (kcal):; Condition 1 (100%): 140 (18.5) kcal; Condition 2 (175%): 155 (22.3) kcal; Condition 3 (250%): 146 (18.2) kcal; P=NS; Entree intake for 5y (g):; Condition 1 (100%): 76.7 (14.8) g; Condition 2 (150%): 100.7 (18.7) g; Condition 3 (200%): 122.7 (21.6) g; P<0.002; Total meal intake for 5y (kcal):; Condition 1 (100%): 186 (18.4) kcal; Condition 2 (150%): 227 (28.8) kcal; Condition 3 (200%): 258 (35.4) kcal; P<0.002 | Model adjustments: NA; Limitations:; - Methods for randomization and concealment NR; No preregistered; data analysis plan; Funding:; NIH; The Nestle R&D Center
Looney, 2011^18^; RCT-Crossover, U.S.; Baseline N=25, Analytic N=17 (Attrition: 32%); Study objective: To investigate the impact of portion size on intake of a lower energy-dense and higher energy-dense snack in preschool-aged children; Participant characteristics at baseline: reschool children, age 2-5y; - [underlined: Age]: 3.8 (0.6) y; - [underlined: Female]: 59%; - [underlined: Race and/or ethnicity]: White: 82%; Nonwhite: 18%; Hispanic: 6%; - [underlined: Socioeconomic position]: Graduate or professional degree: 65%; Caretaker marital status, married: 94%; - [underlined: Anthropometry]: BMI-z score: 0.01 (1.06); [underlined: BMI percentile]: 50.2(32.4)%; - [underlined: Physical activity]: NR; - [underlined: Smoking:] NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Did not receive parental consent, unable to use a spoon, were lactose intolerant, allergic to or disliked study foods, were absent at least 1 data collection day, consumed <5 kcal during a session | Intervention:; [underlined: Condition 1]: Small portion (0.43 kcal/g), applesauce (150 g, 64.5 kcal); [underlined: Condition 2]: Large portion, applesauce (300 g, 129 kcal); [underlined: Condition 3]: Small portion, pudding (1.19 kcal/g) (150 g, 178.5 kcal); [underlined: Condition 4]: Large portion, pudding (300 g, 357 kcal); Duration: 1 snack every other week for 4 sessions; Compliance: 4 excluded for consuming <5kcal in at least 1 session; Outcomes and assessment methods: Before and after test snack; Weighed food intake | Energy intake of the snack:; (pudding and applesauce combined); Small portion (150g): 99.0(52.5) kcal; Large portion (300g): 84.2(30.8) kcal; Main effect of PS: P<0.05; ED: P=NS; PS*ED: P=NS | Model adjustments: NA; - Other: Fixed factors: PS, ED, and order; Limitations:; - Methods for randomization and concealment NR; High rate of attrition, without accounting for missing data; No power calculation; No preregistered data analysis plan; Funding:; None
Carstairs, 2018^8^; RCT-Crossover, U.K.; Baseline N=51, Analytic N=40 (Attrition: 22%); Study objective: To test the effect on intake of reducing the portion size of a high energy dense unit lunch item while varying the variety of the accompanying low energy dense vegetables; Participant characteristics at baseline: 3-5 y old nursery preschoolers; - [underlined: Age]: 3.9 (0.57); - [underlined: Female]: 53%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: Parent education, undergraduate degree: 61% of mothers; HHI >40,000 pounds: 72%; - [underlined: Anthropometry]: BMI: 16.5 kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Children who were allergic to foods served; those who did not attend lunchtime sessions at the nursery on test days; non-eaters (those who consumed <10% of the smallest high energy dense portion on at least 4 occasions) | Intervention:; [underlined: Condition 1]: Familiarization; [underlined: Block 1]: Total meal ED: 1.3 kcal/g; [underlined: Condition 2] :100% PS for HED sandwich, 117g, 3.2 kcal/g; 120g LED cucumber; [underlined: Condition 3]: 100% PS for HED sandwich, 117g, 3.2 kcal/g; 120g LED cherry tomatoes; [underlined: Condition 4]: 100% PS for HED sandwich, 117g, 3.2 kcal/g; 120g LED carrot; [underlined: Condition 5]: 100% PS for HED sandwich, 117g, 3.2 kcal/g; 120g LED cucumber, cherry tomatoes, carrot; [underlined: Block 2]: Total meal ED: 1.1 kcal/g; [underlined: Condition 6]: 60% PS for HED sandwich, 70g, 3.2 kcal/g; 120g LED cucumber; [underlined: Condition 7]: 60% PS for HED sandwich, 70g, 3.2 kcal/g; 120g LED cherry tomatoes; [underlined: Condition 8]: 60% PS for HED sandwich, 70g, 3.2 kcal/g; 120g LED carrot; [underlined: Condition 9]: 60% PS for HED sandwich, 70g, 3.2 kcal/g; 120g LED cucumber, cherry tomatoes, carrot; Duration: 1 meal (lunch) for 8 sessions; Compliance: Two withdrew during the course of study, 6 were non-eaters (<10% of the smallest HED portion on at least 4 occasions), 3 did not complete all 8 conditions; Outcomes and assessment methods: Before and after meal; Weighed food intake | Total Meal Intake (kcal); 60%: 278.0 (10.7) kcal; 100%: 322.0 (16.5) kcal; PS effect x total meal intake: P=0.001; PS effect x sandwich: P<0.001; PS effect x vegetable condition: P=0.877; Interaction PS*vegetable: P=0.590; Vegetable Intake; 60%: 35.1 (5.3) g; 100%: 31.5 (4.1) g; P=0.169; Sandwich Intake:; 60%: 48.4 (2.9) g; 100%: 61.3 (4.4) g; P<0.001 | Model adjustments: NA; Limitations:; - Randomization and concealment methods NR; Did not account for missing data from those lost to follow-up; No preregistered data analysis plan; Funding:; BBSRC, Diet and Nutrition Research Industry Club
Norton, 2015^11^; RCT-Crossover, U.S.; Baseline N=30, Analytic N=26 (Attrition: 13%); Study objective: To examine how beverage type vs. water and beverage portion size influenced beverage intake and food and overall snack energy intake; Participant characteristics at baseline: Preschool children 3y or older, attending childcare; - [underlined: Age]: 3.9 (0.6) y; - [underlined: Female]: 49%; - [underlined: Race and/or ethnicity]: White: 73%; Hispanic or Latino: 11.5%; - [underlined: Socioeconomic position]: Parent education, graduate or professional level: 65%; Married: 92%; - [underlined: Anthropometry]: BMI percentile: 62.2 (20.5)%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Under 3 y of age by the start of the study, not enrolled at the on-campus childcare, allergies to or dislike of the foods used in the study, not able to use a spoon, no parental consent | Intervention:; [underlined: Condition 1]: Small juice (100%, 6oz), applesauce, graham crackers (369 kcal); [underlined: Condition 2]: Large juice (200%, 12oz), applesauce, graham crackers (459 kcal); [underlined: Condition 3]: Small water (100%, 6oz), applesauce, graham crackers (279 kcal); [underlined: Condition 4:] Large water (200%, 12oz), applesauce, graham crackers (279 kcal); Duration: 1 meal (snack) for 4 sessions; Compliance: One excluded for consuming all foods provided, 3 excluded for being absent during test sessions; Outcomes and assessment methods: Before and after the test meal; Weighed food intake | Beverage intake (g and/or kcal):; Main effect of beverage portion size, large vs small: 173.9 (101.7) g vs. 121.3 (59.9) g, P<0.01; Main effect of beverage type, juice vs water: 184.9 (82.8) g vs. 110.5 (71.9) g, P<0.001; Food intake (g and/or kcal):; [underlined: Condition 1 (small juice)]: NR; [underlined: Condition 2 (large juice)]: 88.5 (64.1) kcal; [underlined: Condition 3 (small water)]: NR; [underlined: Condition 4 (large water)]: 117.7 (69.1) kcal; Main effect of beverage portion size, type interaction: P<0.05; Main effect of beverage portion size: P=NS; Main effect of beverage type: P=NS; Total energy intake at snack (kcal): Main effect of beverage type, juice vs. water: 175.4 (50) kcal vs 104.8 (62.8) kcal, P=NS; Main effect of beverage portion size: P=NS | Model adjustments: NA; Limitations:; - No power calculation; No preregistered data analysis plan; Funding: NR
Reale, 2018^26^; RCT-Parallel, U.K.; Baseline N=47, Analytic N=46 (Attrition: 2%); Study objective: To explore the feasibility and acceptability of two strategies of snack portion control: snack reduction and snack replacement; the secondary aim was to examine the efficacy of the two methods of portion size reduction to improve the diets of preschool children; Participant characteristics at baseline: Mothers (at least 18 y) of children aged 22-56 months who reported being primarily responsible for feeding their child; - [underlined: Age]: 36.6 (9.5) months; - [underlined: Female]: 48%; - [underlined: Race and/or ethnicity]: Chinese: 4% Asian Indian: 2%; White British, mixed, or other: 94%; - [underlined: Socioeconomic position]: Parent education, >A-level or equivalents: 74%; HHI, £30-40,000: 24%; £40,000+: 22%; Married/cohabiting: 100%;; Employment status: 63% employed fulltime/part time or on maternity leave; - [underlined: Anthropometry]: BMI percentile: 60.9 (26.7); - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Child not consuming at least 1 high energy dense commercially available snack per day, could not commit to the 3-week study, child not likely or not familiar with study snack items, child had a food allergy or were taking medications known to impact appetite, child attended nursery for more than 3 full consecutive days | Intervention:; [underlined: Group 1]: Snack Reduction; Week 1: Baseline; Week 2: Acclimation, replace HED snacks with study snacks; Week 3: Snack reduction, replaced HED snacks with study snacks and reduced portion size by 50%; [underlined: Group 2]: Snack Replacement; Week 1: Baseline; Week 2: Acclimation, replaced HED snacks with study snacks; Week 3: Snack replacement, replaced HED snacks with 40g of fruits and vegetables and starch-based foods; Duration: 3 weeks, all snacks (kept normal snacking routines); Compliance: 98% participation at week 3; total compliance was associated with study week but not condition. Compliance to the snacking schedule was higher in week 3 compared to week 2.; Outcomes and assessment methods: Weekly; 4-day weighed food diary | Snack Reduction, Mean (SD); Week 1, 100%: 1052.1 (235.8) kcal; Week 2, 100%: 1077.8 (229.1) kcal; Week 3, 50%: 1063.5 (284.1) kcal; p=NS | Model adjustments: NA; - Other: Study week was within subject’s variable and intervention group was between group; Limitations:; - Concerns with concealment; deviations from intended intervention with free-living environment (not accounting for compliance and consumption of other non-snack foods); Concerns with outcome measurement method due to use of food diary for outcome; Funding: BBSRC, Diet and Nutrition Research Industry Club
Orlet Fisher, 2003^24^; RCT-crossover, U.S.; Baseline N=35, Analytic N=30 (Attrition: 14%); Study objective: To determine the effects of repeated exposure to a large portion of an entrée on preschool aged children’s awareness of portion size, self-selected portion size, and food intake and to evaluate associations of children’s responsiveness to portion size with weight status and overeating; Participant characteristics at baseline: Preschool; - [underlined: Age]: 4.0 (0.5) y; (Range: 2.9-5.1y); - [underlined: Female]: 51%; - [underlined: Race and/or ethnicity]: White, nonHispanic: 80%; African American: 3%; Asian: 11%; Hispanic: 6%; - [underlined: Socioeconomic position]: 4y University degree: 81% of mothers, 90% of fathers; HHI >$50k: 68%; Current employment: 84% of mothers, 90% of fathers; - [underlined: Anthropometry]: NR; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Parents did not give permission | Intervention:; [underlined: Condition 1]: 100% entrée (125 g, 463 kcal for <4y, 175 g, 648 kcal for >4y); [underlined: Condition 2:] 200% entrée (250 g, 925 kcal for <4y, 350 g, 1295 kcal for >4y); [underlined: Condition 3:] Self-selected; Entrees (macaroni and cheese) were served with a fixed amount of carrot sticks, apple, sugar cookies, and milk; Duration: 1 meal (lunch) once a week for 12 weeks (each condition served 4 times); Compliance: Five excluded for consuming <10g of entrée; Outcomes and assessment methods: Before and after test meal; Weighed food intake | Entree intake (kcal):; Condition 1 (100%) vs Condition 2 (200%): 25 (7) % increase in kcal, P<0.001; Intake of other foods served at the meal:; Condition 1 (100%): 167 (15) kcal; Condition 2 (200%): 163 (14) kcal; P=0.91; Total energy intake at lunch:; Condition 1 (100%): 544 (26) kcal; Condition 2 (200%): 622 (37) kcal; P<0.01 | Model adjustments: NA; Limitations:; - No preregistered data analysis plan; Funding:; USDA
Kling, 2016a^9^; RCT-Crossover, U.S.; Baseline N=143, Analytic N=125 (Attrition: 13%); Study objective: To test the effects of varying the energy density and portion size of milk consumed with a lunch meal on energy intake in preschool children; Participant characteristics at baseline: Preschool children; - [underlined: Age]: 4.2 (0.1) y; - [underlined: Female]: 46%; - [underlined: Race and/or ethnicity]: White: 75%; Black or African American: 3%; Asian: 15%; Mixed or another race: 7%; Hispanic or Latino: 8%; - [underlined: Socioeconomic position]: College degree or higher: 92% of mothers, 86% of fathers; HHI >$50,000: 72%; - [underlined: Anthropometry]: BMI percentile: 53.6 2.4)%; [underlined: BMI z-score]: 0.12 (0.13) boys; 0.04 (0.11) girls; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Allergy or intolerance to study foods or milk being served. | Intervention:; [underlined: Condition 1]: 100% portion size (6 fl. oz), lower energy density (1% milk); [underlined: Condition 2]: 150% portion size (9 fl. oz), lower energy density (1% milk); [underlined: Condition 3]: 100% portion size (6 fl. oz), higher energy density (whole milk); [underlined: Condition 4]: 150% portion size (9 fl. oz), higher energy density (whole milk); Milk and all lunch foods (macaroni and cheese, chicken nuggets, broccoli, bananas) were consumed ad libitum; Duration: 1 meal (lunch) for 4 sessions; Compliance: Eight children were excluded for being absent for 2 or more meals, 10 children were excluded for not consuming a minimum amount of milk; Outcomes and assessment methods: Before and after test meal; Weighed food intake | Milk intake (kcal), total meal intake (kcal):; [underlined: Condition 1 (100% PS, lower ED)]: 63(2), 22(8); [underlined: Condition 2 (150% PS, lower ED)]: 79(3), 337(10); [underlined: Condition 3 (100% PS, higher ED)]: 90(3), 328(9); [underlined: Condition 4 (150% PS, higher ED)]: 113(4), 337(10); Energy density: P<0.003, NS; Portion size: P<0.04, NS; Sex: In boys, meal energy intake did not differ by milk ED. In girls, higher milk ED led to significant increases in meal energy intake (24 (10) kcal, P=0.03) | Model adjustments: NA; Limitations:; - Methods for randomization and concealment NR; Funding:; NIH, USDA
Diktas, 2021^6^; RCT-Crossover, U.S.; Baseline N=NR, Analytic N=67 (Attrition: NR); Study objective: To test the independent and combined effects on preschool children’s vegetable intake of serving a larger portion of vegetables and enhancing their flavor; Participant characteristics at baseline: reschool children; - [underlined: Age]: 4.2 (0.6) y (Range: 3-5y); - [underlined: Female]: 61%; - [underlined: Race and/or ethnicity]: White: 77.3%; Black or African American: 4.6%; Asian: 7.6%; Mixed or another race: 10.6%; Hispanic or Latino: 10.6%; - [underlined: Socioeconomic position]: University degree: 85% of mothers and 78% of fathers; >$50k: 75%; - [underlined: Anthropometry]: BMI z-score: 0.1 (1) BMI-for-age percentile: 54 (27)%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: NR | Intervention:; [underlined: Condition 1:] 100% portion size, plain vegetables (lower ED, 0.42/1.26 kcal/g); [underlined: Condition 2]: 100% portion size, enhanced vegetables (higher ED, 0.58/1.42 kcal/g); [underlined: Condition 3]: 200% portion size, plain vegetables (lower ED, 0.42/1.26 kcal/g); [underlined: Condition 4]: 200% portion size, enhanced vegetables (higher ED, 0.58/1.42 kcal/g); Lunch meal included corn and broccoli (PS and ED manipulated) with fish sticks, rice, applesauce, ketchup, milk (portions held constant).; Duration: 1 meal (lunch) for 4 sessions; Compliance: NR; Outcomes and assessment methods: Before and after test meal; Weighed food intake | Condition 1 (100% PS, low ED):; Broccoli: 8 (1) kcal; Corn: 18 (2) kcal; Total meal: 262 (10) kcal; Condition 2 (100% PS, high ED):; Broccoli: 10 (1) kcal; Corn: 19 (2) kcal; Total meal: 277 (8); Condition 3 (200% PS, low ED):; Broccoli: 13 (2) kcal; Corn: 35 (3) kcal; Total meal: 282 (10) kcal; Condition 4 (200% PS, high ED):; Broccoli: 16 (2) kcal; Corn: 30 (3) kcal; Total meal: 284 (11) kcal; Broccoli: PS effect: P<0.0001, ED effect: P=0.0002; Corn: PS effect: P<0.0001, ED effect: P=0.25; Broccoli: PS effect: P=0.018, ED effect: P=0.10 | Model adjustments: NA; Limitations:; - Did not describe baseline sample size or attrition; Funding:; NIH
Savage, 2012^16^; RCT-crossover , U.S.; Baseline N=21, Analytic N=17 (Attrition: 19%); Study objective: To assess the effect of serving a range of entrée portions on children’s ad libitum intake and energy density consumed at the meal; Participant characteristics at baseline: 3-5 y old children at a full-day childcare center; - [underlined: Age]: 4.3 (0.5) y; - [underlined: Female]: 59%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: Parents tended to be highly educated; HHI >$50,000: 60%; Parent marital status, married: 70%; - [underlined: Anthropometry]: BMI percentile: 74.6 (18.9); >85th percentile: 35%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Presence of food intolerance to study food, chronic illnesses affecting food intake, consuming <22g of the entree (<10%), dislike of the main entree, uncooperative behavior during lunch, non-English speaking, extended absences | Intervention:; [underlined: Condition 1]: 100g (100%); [underlined: Condition 2]: 160g (160%); [underlined: Condition 3]: 220g (220%); [underlined: Condition 4]: 280g (280%); [underlined: Condition 5]: 340g (340%); [underlined: Condition 6]: 400g (400%); Duration: 1 meal (lunch) 6 weeks; Compliance: Four excluded for not meeting predefined attendance criteria; Outcomes and assessment methods: Before and after test meals; Weighed food intake | Energy intake from the entree: Condition 1 (100%): 144.7 kcal; Condition 2 (160%): 233.2 kcal; Condition 3 (220%): 261.3 kcal; Condition 4 (280%): 302.3 kcal; Condition 5 (340%): 356.1 kcal; Condition 6 (400%): 389.7 kcal; P<0.0001; Total energy intake at the meal:; Condition 1: 314.9 kcal; Condition 2: 400.9 kcal; Condition 3: 418.4 kcal; Condition 4: 434.7 kcal; Condition 5: 498.7 kcal; Condition 6: 505.8 kcal; P<0.001; Energy intake from other foods:; [underlined: Energy intake from unsweetened applesauce]:; Condition 1: 56.6 kcal; Condition 2: 50.4 kcal; Condition 3: 49.0 kcal; Condition 4: 41.6 kcal; Condition 5: 31.3 kcal; Condition 6: 33.2 kcal; P<0.0001; [underlined: Energy intake from green beans]:; Condition 1: 7.6 kcal; Condition 2: 7.8 kcal; Condition 3: 6.1 kcal; Condition 4: 7.3 kcal; Condition 5: 5.6 kcal; Condition 6: 2.7 kcal; P=0.05; [underlined: Energy intake from the whole-wheat roll]:; Condition 1: 54.6 kcal; Condition 2: 52.2 kcal; Condition 3: 38.7 kcal; Condition 4: 24.1 kcal; Condition 5: 41.9 kcal; Condition 6: 26.1 kcal; P<0.001; [underlined: Energy intake from milk]:; Condition 1: 51.4 kcal; Condition 2: 57.4 kcal; Condition 3: 63.3 kcal; Condition 4: 59.5 kcal; Condition 5: 63.8 kcal; Condition 6: 53.9 kcal; P=NS | Model adjustments: NA; - Other: Random factors: child classroom, lunch table, day of the week lunch was eaten, session order; Limitations:; - Methods for randomization and concealment NR; High attrition rate, not accounted for in analyses; No power calculation; No preregistered data analysis plan; Funding:; NIH
Kling, 2016b^10^; RCT-Crossover, U.S.; Baseline N=131, Analytic N=120 (Attrition: 8%); Study objective: To test the effects on intake of varying the portion size and ED of lunches served to children in their usual eating environment; Participant characteristics at baseline: Children, age 3-6y; - [underlined: Age]: 4.4 (0.1) y; - [underlined: Female]: 49%; - [underlined: Race and/or ethnicity]: White: 69%; Black or African American: 3%; Asian: 21%; Mixed or another race: 7%; Hispanic or Latino: 4%; - [underlined: Socioeconomic position]: Parent education, bachelor’s degree or higher: 92% of Mothers; 90% of Fathers; HHI >$50,000: 69%; - [underlined: Anthropometry]: BMI percentile: 56.8 (2.6)%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Allergy or intolerance to foods and milk being served; those absent for >3 of the 6 study days | Intervention:; [underlined: Condition 1]: 100% portion size, low energy density (100%); [underlined: Condition 2]: 150% portion size, low energy density (100%); [underlined: Condition 3]: 200% portion size, low energy density (100%); [underlined: Condition 4]: 100% portion size, high energy density (142%); [underlined: Condition 5]: 150% portion size, high energy density (142%); [underlined: Condition 6]: 200% portion size, high energy density (142%); Duration: 1 meal (lunch) for 6 sessions; Compliance: Eleven participants were absent >3 of the 6 experimental meals; Outcomes and assessment methods: Before and after test meal; Weighed food intake | Total Meal energy intake (kcal):; 100% PS, 100% ED: 222 (9); 150% PS, 100% ED: 279 (11); 200% PS, 100% ED: 279 (12); 100% PS, 142% ED: 321 (12); 150% PS, 142% ED: 366 (14); 200% PS, 142% ED: 390 (15); Main effect of PS: P<0.0001 (100% vs 150%, 200%; P=NS for 150% vs 200%); Main effect of ED: P<0.0001; PS, ED interaction: P<0.05; Energy intake of chicken (kcal):; 100% PS, 100% ED: 48 (4); 150% PS, 100% ED: 47 (4); 200% PS, 100% ED: 44 (4); 100% PS, 142% ED: 95 (5); 150% PS, 142% ED: 95 (7); 200% PS, 142% ED: 106 (8); PS: P=NS; ED: P<0.02; Energy intake from macaroni and cheese (kcal):; 100% PS, 100% ED: 86 (6); 150% PS, 100% ED: 117 (8); 200% PS, 100% ED: 116 (9); 100% PS, 142% ED: 102 (8); 150% PS, 142% ED: 119 (10); 200% PS, 142% ED: 127 (12); PS: P<0.03; ED: P<0.02; Energy intake from vegetable, (kcal):; 100% PS, 100% ED: 12 (1); 150% PS, 100% ED: 12 (2); 200% PS, 100% ED: 11 (2); 100% PS, 142% ED: 15 (2); 150% PS, 142% ED: 15 (2); 200% PS, 142% ED: 16 (2); PS: P=NS; ED: P<0.02; Energy intake from applesauce (kcal):; 100% PS, 100% ED: 36 (2); 150% PS, 100% ED: 49 (3); 200% PS, 100% ED: 60 (3); 100% PS, 142% ED: 50 (2); 150% PS, 142% ED: 70 (4); 200% PS, 142% ED: 79 (5); PS: P<0.03; ED: P<0.02; Energy intake from ketchup (kcal):; 100% PS, 100% ED: 6 (1); 150% PS, 100% ED: 8 (1); 200% PS, 100% ED: 8 (1); 100% PS, 142% ED: 9 (1); 150% PS, 142% ED: 12 (1); 200% PS, 142% ED: 14 (1); PS: P<0.05; ED: P<0.02; Energy intake from milk (kcal):; 100% PS, 100% ED: 35 (3); 150% PS, 100% ED: 46 (4); 200% PS, 100% ED: 41 (4); 100% PS, 142% ED: 50 (4); 150% PS, 142% ED: 56 (5); 200% PS, 142% ED: 51 (5); PS: P<0.03; ED: P<0.02 | Model adjustments: NA; - Other: Fixed factors in model: PS, ED, study week, and classroom, significant interactions; Limitations:; - None identified; Funding:; NIH
Spill, 2010^19^; RCT-crossover, U.S.; Baseline N=51, Analytic N=51 (Attrition: 0%); Study objective: To test whether increasing the portion size of vegetables served at the start of a meal leads to increased vegetable consumption and decreased meal energy intake in children; Participant characteristics at baseline: Children, aged 3-6y enrolled in daycare; - [underlined: Age]: 4.4 (0.1) y; - [underlined: Female]: 57%; - [underlined: Race and/or ethnicity]: White: 61%; Black or African American: 7%; Asian: 30%; American Indian or Alaska Native: 2%; - [underlined: Socioeconomic position]: College degree: 90% (mothers); 85% (fathers); >$50,000: 79%; - [underlined: Anthropometry]: BMI-for-age percentile: 63.5 (3.7); Overweight or obese: 24%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: NR | Intervention:; [underlined: Condition 1]: No carrots or ranch dip; [underlined: Condition 2]: Carrots (100%, 30 g, 12 kcal), ranch dip (30 g, 20 kcal); [underlined: Condition 3]: Carrots (200%, 60 g, 24 kcal), ranch dip (30 g, 20 kcal); [underlined: Condition 4]: Carrots (300%, 90 g, 36 kcal), ranch dip (30 g, 20 kcal); Duration: 1 meal (first course, lunch, afternoon snack) once a week for 4 weeks; Compliance: N/A; Outcomes and assessment methods: Before and after test meal; Weighed food intake | Energy intake from carrots:; [underlined: Condition 1]: 0 kcal (no carrots provided); [underlined: Condition 2 (100%)]: 8.7 (0.4) kcal; [underlined: Condition 3 (200%)]: 12.8 (0.9) kcal; [underlined: Condition 4 (300%)]: 13.5 (1.1) kcal; Condition 2 vs 3, P<0.003; Condition 2 vs 4, P<0.003; Condition 3 vs 4, P=NS; Energy intake from lunch, P=NS across conditions; Energy intake from broccoli, P=NS across conditions; Total energy intake from carrots and lunch, P=NS across conditions | Model adjustments: NA; - Other: Portion size and session number; Limitations:; - Methods for randomization and concealment NR; Inclusion/exclusion criteria NR; No preregistered data analysis plan; Funding:; NIH; Robert Wood Johnson Foundation
Smethers, 2019^7^; RCT-Crossover, U.S.; Baseline N=50, Analytic N=46 (Attrition: 8%); Study objective: To test whether the portion size effect is sustained in preschool children across 5 days; Participant characteristics at baseline: Children, 3-5 y, attending childcare; - [underlined: Age]: 4.4 (0.6) y; - [underlined: Female]: 35%; - [underlined: Race and/or ethnicity]: White: 74%; Asian: 9%; Mixed or other race: 6%; Hispanic or Latino: 13%; - [underlined: Socioeconomic position]: Parent education, college or higher: 96% of mothers, 84% of fathers; HHI >$50k: 76%; - [underlined: Anthropometry]: BMI-for-age percentile: 52.8 (24.5)%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Food allergies, food restrictions, or health issues that precluded their participation or if they were not available for the duration of the study | Intervention:; Condition 1: 100% portions; Condition 2: 150% portions; Duration: 5 days for 2 sessions; Compliance: Four excluded for not meeting predefined attendance criteria; Outcomes and assessment methods: Before and after the test meals; Weighed food intake | Daily energy intake, Condition 1 (100%), Condition 2 (150%), P-value; [underlined: All food]: 758 (36), 900 (36), P<0.0001; [underlined: Food at main meals]: 459 (23), 515 (23), P<0.0001; [underlined: Main dish]: 289 (16), 329 (16), P<0.0001; [underlined: Vegetable]: 55 (5), 59 (5), P=0.12; [underlined: Fruit]: 95 (7), 106 (7), P=0.02; [underlined: Condiments]: 22 (2), 26 (2), P=0.002; [underlined: Food at snacks]: 306 (18), 388 (18), P<0.0001; [underlined: Grain-based snacks]: 230 (15), 291 (15), P<0.0001; [underlined: Dairy snacks]: 63 (5), 81 (5), P<0.0001; [underlined: Fruit and vegetable snacks]: 16 (2), 20 (2), P=0.006; [underlined: All milk]: 153 (13), 178 (13), P=0.0004; [underlined: Milk at main meals]: 117 (11), 128 (11), P=0.06; [underlined: Milk at snacks]: 36 (2), 49 (2), P<0.0001; [underlined: All food and milk]: 914 (44), 1081 (44), P<0.0001; [underlined: Food and milk at main meals]: 577 (29), 644 (29), P<0.0001; [underlined: Food and milk at snacks]: 341 (19), 437 (19), P<0.0001 | Model adjustments: NA; Limitations:; - None identified; Funding:; NIH, USDA
Roe, 2022^5^; RCT-Crossover, U.S.; Baseline N=57, Analytic N=53 (Attrition: 7%); Study objective: To test the effects on children’s intake of two strategies for increasing the proportion of vegetables and fruits: either adding or substituting extra portions as side dishes at meals and snacks over five days; Participant characteristics at baseline: Aged 3-5 y in classrooms of childcare center; - [underlined: Age]: 4.4 (1.1) y; - [underlined: Female]: 47%; - [underlined: Race and/or ethnicity]: White: 58%; Black: 4%; Asian: 13%; Mixed or another race: 13%; Hispanic or Latino: 6%; - [underlined: Socioeconomic position]: Parent education, at least undergraduate degree: 85% of Mothers; 75% of Fathers;; >$50,000 HHI: 70%; - [underlined: Anthropometry]:; BMI z-score: 0.12 (1.12); BMI percentile: 56.1 (4.1)%; Overweight or obesity: 16%; - [underlined: Physical activity]: Mean daily step counts; Control: 5180 (164); Addition: 4868 (160); Substitution: 5092 (165); p=0.07 (Step count not related to effect on daily energy intake of the proportion of fruits and vegetables served); - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Not available for duration of study, followed a diet that excluded study foods served, food allergy to foods served | Intervention:; [underlined: Addition]: Increased portion sizes of vegetables and fruits by 50%, with no change in other foods served; [underlined: Substitution]: Increased the portion size of vegetables and fruits by 50%, and decreased the portion sizes of all other foods served by an equivalent weight; [underlined: Control]: Typical portions in all food groups to meet CACFP requirements; Duration: 5 days for 3 sessions; Compliance: Four participants withdrew because of scheduling conflicts or moving to another childcare center; Outcomes and assessment methods: Before and after each meal or session; Weighed food intake | Fruit and vegetable intake, kcal not reported:; Intake was significantly higher in the substitution condition vs addition and control, and in the addition condition vs. control (P<0.0001); Energy Intake, kcal:; [underlined: Food Only]; Control: 925 (33); Addition: 981 (33); Substitution: 864 (33); p<0.0001; [underlined: Milk Only]; Control: 130 (10); Addition: 132 (10); Substitution: 129 (10); p=0.97; [underlined: Food and Milk]; Control: 1054 (35); Addition: 1111 (35); Substitution: 990 (35); p<0.0001; Energy intake across 5 days:; Substitution<Control<Addition, p<0.0001 | Model adjustments: NA; - Other: Fixed factors in models were experimental condition, study week, study day, menu, childcare center, classroom, false discovery rate; Limitations:; - None identified; Funding:; NIH
Spill, 2011^17^; RCT-crossover, U.S.; Baseline N=73, Analytic N=72 (Attrition: 1%); Study objective: To test whether varying the portion of low-energy-dense vegetable soup served at the start of a meal affects meal energy and vegetable intakes in children; Participant characteristics at baseline: Children, aged 3-6y enrolled in daycare; - [underlined: Age]: 4.7 (0.1) y; (Range: 3.3-5.7 y); - [underlined: Female]: 57%; - [underlined: Race and/or ethnicity]: White: 67%; Black or African American: 6%; Asian: 27%; - [underlined: Socioeconomic position]: Parent education, college degree: 95% (mothers); 88% (fathers); HHI >$50,000: 70%; - [underlined: Anthropometry]:; BMI-for-age percentile: 59.8 (3.4)%;; Range (1.4-99.0)%;; Overweight/obese: 27%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: NA | Intervention:; [underlined: Condition 1]: No soup; [underlined: Condition 2]: 100% (150 g, 56 kcal); [underlined: Condition 3]: 150% (225 g, 83 kcal); [underlined: Condition 4]: 200% (300 g, 111 kcal); Children were served fixed breakfast, lunch main course, and afternoon snack.; Duration: 1 meal (first course, lunch, afternoon snack) once a week for 4 weeks; Compliance: One was excluded for undue influence on the results because of high variability across meals; Outcomes and assessment methods: Before and after test meal; Weighed food intake | Energy intake from the soup:; [underlined: Condition 1 (no soup)]: 0 kcal; [underlined: Condition 2 (100%)]: 39.8 (2.2) kcal; [underlined: Condition 3 (150%)]: 44.8 (3.3) kcal; [underlined: Condition 4 (200%)]: 48.8 (3.8) kcal; Condition 2 vs. 3, 4; p<0.0001; Condition 3 vs. 4; NS; Energy intake from lunch:; [underlined: Condition 1]: 385 (24.2) kcal; [underlined: Condition 2]: 292.4 (21.8) kcal; [underlined: Condition 3]: 325.9 (22.5) kcal; [underlined: Condition 4]: 334.0 (21.7) kcal; Condition 1 vs. 2, 3, 4; p<0.0001; Energy intake from soup + lunch:; [underlined: Condition 1]: 491.0 (25.1) kcal; [underlined: Condition 2]: 436.5 (23.2) kcal; [underlined: Condition 3]: 467.2 (23.0) kcal; [underlined: Condition 4]: 478.8 (24.3) kcal; Condition 1 vs. 2; p<0.05; Condition 2 vs. 4; p<0.05; Energy intake from afternoon snack:; [underlined: Condition 1]: 34.9 (5.8) kcal; [underlined: Condition 2]: 33.8 (5.2) kcal; [underlined: Condition 3]: 39.4 (5.7) kcal; [underlined: Condition 4]: 51.3 (6.6) kcal; Condition 1, 2, 3 vs. 4; P<0.05 | Model adjustments: NA; - Other: Portion size, classroom, test session; Limitations:; - Methods for randomization and concealment NR; Inclusion/exclusion criteria unclear; No preregistered data analysis plan; Funding:; NR
McCrickerd, 2017^27^; NRCT, Singapore; Baseline N=37, Analytic N=22 (Attrition: 41%); Study objective: To investigate whether the portions teachers serve to children i.) differ from those children would serve themselves and ii.) impact food intake; Participant characteristics at baseline: Preschool-aged, 3.0-6.8 years old; - [underlined: Age]: 4.9 (1.3) y; - [underlined: Female]: 46%; - [underlined: Race and/or ethnicity]: Likely majority; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI percentile: 44.2 (27.5)%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Missing data due to children being absent for 1 or more study sessions | Intervention:; [underlined: Condition 1]: 100%, teacher served; [underlined: Condition 2]: 150%, teacher served; Energy density of meals inadvertently varied in some conditions; results reported separately for equal and varied ED; Duration: 1 meal (lunch) for 6 sessions; Compliance: Fifteen were absent >1 testing day; Outcomes and assessment methods: Before and after meals; Weighed food intake | Equal Energy Density Meals[underlined: Energy intake (kcal)]:; Energy intake was significantly greater when children were served 150% vs 100%, P<0.01; Varied Energy Density Meals; The amount of food consumed was significantly greater when children were served 150% vs 100%, P<0.01; Energy intake did not differ significantly when children were served 150%, ED 1.65 kcal/g vs. 100% 1.30 kcal/g, P=NS | Model adjustments:; - TEI: NR; - Key confounders: Sex, Age, Energy intake; Limitations:; - Did not account for all key confounders; Concerns related to deviations from the intended intervention because energy density inadvertently varied between conditions; No power calculation; No preregistered data analysis plan; Funding:; NR
Mathias, 2012^15^; RCT-Crossover, U.S.; Baseline N=38, Analytic N=30 (Attrition: 21%); Study objective: To evaluate the effects of vegetable portion size, fruit portion size, and their interaction on children’s food and energy intakes at dinner meals; Participant characteristics at baseline: Children, 4-6y; - [underlined: Age]: 5.4 (0.2) y; - [underlined: Female]: 60%; - [underlined: Race and/or ethnicity]: Non-Hispanic; White: 30%; Non-Hispanic Black/African; American: 47%; Hispanic White: 23%; - [underlined: Socioeconomic position]: NR; Parent employment, part-time or full-time: 50%; - [underlined: Anthropometry]:; BMI-for-age-percentile: 72.3 (5.4)%; >85th percentile: 50%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Disliked study foods; those who ate negligible amounts of FVs; had severe food allergies, chronic illnesses, conditions affecting food intake, or were receiving a special diet | Intervention:; [underlined: Condition 1]: 100% fruit and vegetable (75g, 45 kcal each); [underlined: Condition 2]: 200% vegetable (150g, 90 kcal); [underlined: Condition 3]: 200% fruit (150g, 90 kcal); [underlined: Condition 4]: 200% fruit and vegetable (150g, 90 kcal each); Amounts of milk and main entree were fixed.; Duration: 1 meal (dinner) once a week for 5 sessions; Compliance: Three excluded for disliking main entree, 1 for disliking both FVs, 4 excluded for eating a negligible amount of fruit/vegetables at more than half of the visits.; Outcomes and assessment methods: Before and after test meal; Weighed food intake | Total energy intake at the meal:; [underlined: Condition 1]: 368 (33) kcal; [underlined: Condition 2]: 366 (33) kcal; [underlined: Condition 3]: 383 (34) kcal; [underlined: Condition 4]: 342 (34) kcal; P=NS; Energy intake from the fruit and vegetables:; Condition 1 vs. Condition: 35.5 (3)kcal vs. 60.6 (5.4) kcal, P<0.0001; Condition 1 vs. Condition 3: 19.2 (3.6) kcal vs. 26.4 (5.4) kcal, P<0.01; Condition 1 vs. Condition: 58 (5) kcal vs. 88 (9) kcal, P<0.0001; Energy intake from the entree: Condition 1 vs. Condition 4: 172 (27) kcal vs. 217 (26) kcal, P<0.05 | Model adjustments: NA; Limitations:; - Methods for randomization and concealment NR; Attrition high (but adequately powered); Did not account for the effects of those excluded due to not consuming enough study foods; No preregistered data analysis plan; Funding:; NIH
Mooreville, 2015^12^; RCT-Crossover, U.S.; Baseline N=NR, Analytic N=100 (Attrition: NR); Study objective: To determine the association of children’s susceptibility to large food portion sizes with appetite regulation and obesity; Participant characteristics at baseline: Children, 5-6 y, “normal” weight or with obesity; - [underlined: Age]: 5.4 (0.5) y; - [underlined: Female]: 55%; - [underlined: Race and/or ethnicity]: Black, nonHispanic: 100%; - [underlined: Socioeconomic position]: Parent education, beyond high school: 58%; NR;; Participating in federal assistance programs: 85%; - [underlined: Anthropometry]:; BMI-for-age percentile: 98.12 (1.6)% for those with obesity;; 58.99 (23.4)% for those with “normal” weight; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Underweight or overweight, race other than non-Hispanic Black, dislike of study foods, medical conditions (e.g., Sickle cell anemia, diabetes), medication use (e.g., corticosteroids), developmental delays, or severe food allergies (e.g., gluten) known to affect food intake or growth | Intervention:; [underlined: Condition 1]: 100% portion sizes, 677 kcal; [underlined: Condition 2]: 150% portion sizes, 1015 kcal; [underlined: Condition 3]: 200% portion sizes, 1353 kcal; [underlined: Condition 4]: 250% portion sizes, 1691 kcal; Duration: 1 meal (dinner) for 4 sessions; Compliance: Two children missed the 100% portion size condition, 2 children missed the 150% portion size condition, 1 child missed the 200% portion size condition; Outcomes and assessment methods: Before and after the test meal; Weighed food intake | Energy intake from macaroni and cheese:; [underlined: Condition 1]: 262.5(147.7) kcal; [underlined: Condition 2]: 299.61(190.0) kcal; [underlined: Condition 3]: 282.9(212.9) kcal [underlined: Condition 4]: 317.0(234.2) kcal; P<0.05; Energy intake from corn:; [underlined: Condition 1]: 30.4 (25.4) kcal; [underlined: Condition 2]: 23.0 (31.3) kcal; [underlined: Condition 3]: 35.9 (38.5) kcal; [underlined: Condition 4]: 29.9 (36.0) kcal; P=NS; Energy intake from applesauce:; [underlined: Condition 1]: 26.1 (19.5) kcal; [underlined: Condition 2]: 26.7 (26.7) kcal; [underlined: Condition 3]: 30.1 (31.9) kcal; [underlined: Condition 4]: 25.2 (31.4) kcal; P=NS; Energy intake from cookies:; [underlined: Condition 1]: 88.2 (40.8) kcal; [underlined: Condition 2]: 109.1(63.1) kcal; [underlined: Condition 3]: 126.0(78.3) kcal; [underlined: Condition 4]: 140.4(102.6) kcal; P<0.0001; Energy intake from milk, did not differ significantly across conditions, P=NS; Total energy intake at dinner: [underlined: Condition 1]: 479.9 (167.8) kcal; [underlined: Condition 2]: 531.2 (204.9) kcal; [underlined: Condition 3]: 540.9 (216.5) kcal; [underlined: Condition 4]: 585.1 (247.8) kcal; P<0.001 | Model adjustments: NA; Limitations:; - Methods for randomization and concealment NR; Did not describe attrition; No power calculation; No preregistered data analysis plan; Funding:; NIH
Kral, 2010^20^; RCT-crossover , U.S.; Baseline N=43, Analytic N=43 (Attrition: 0%); Study objective: To examine the effects of increasing the portion size of F&V side dishes on children’s intake; Participant characteristics at baseline: Children, between 5-6y with BMI-for-age >5th percentile; - [underlined: Age]: 5.9 (0.6) y; - [underlined: Female]: 49%; - [underlined: Race and/or ethnicity]: White: 11.6%; Black or African American: 76.7%; More than one race: 11.6%; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 17.0 (2.5) kg/m^2^; BMI z-score: 0.73 (1.1); BMI-for-age percentile: 5th to 84th, 62.8%; 85th to 94th, 20.9%; >95th, 16.3%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Did not like study foods, had a serious medical condition known to affect food intake and body weight, developmental, medical, or psychiatric conditions that might impact study compliance, food allergies, taking medications know to affect food or body weight | Intervention:; [underlined: Condition 1]: 100% each of broccoli, (75g, 22kcal), carrots (75g, 22kcal), and applesauce (122g, 49kcal) (626 kcal); [underlined: Condition 2]: 200% each of broccoli (150g, 44kcal), carrots (150g, 44kcal), and applesauce (244g, 133kcal) (719 kcal); Duration: 1 meal (dinner) once a week for 2 weeks; Compliance: NA; Outcomes and assessment methods: Before and after test meal; Weighed food intake | Energy intake from vegetable and fruit sides:; Broccoli: Condition 1 (100%) vs. Condition 2 (200%), P=NS; Carrots: Condition 1 vs. Condition 2, P=NS; Applesauce: Condition 2 vs. Condition 1, +15 (4) kcal, P=0.001; Energy intake from entree:; Condition 2 vs. Condition 1: −36 (17) kcal, P=0.04; Energy intake from milk:; Condition 1 vs. Condition 2: P=NS; Total meal energy intake:; Condition 1, 100%: 446 (19) kcal; Condition 2, 200%: 426 (19) kcal; P=NS | Model adjustments:; - Other: Fixed factor effects were portion size condition and time (week). If significant, interaction between portion size condition and time; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; The Obesity Society
Fisher, 2007b^22^; RCT-Crossover, U.S.; Baseline N=53, Analytic N=53 (Attrition: 0%); Study objective: To test the effects of entrée portion size and ED on satiation in preschool children; Participant characteristics at baseline: Preschool children; - [underlined: Age]: 5-6y; - [underlined: Female]: 53%; - [underlined: Race and/or ethnicity]: Non-Hispanic; White: 30%; Non-Hispanic Black: 38%;; Other: 4%; Hispanic: 28%; - [underlined: Socioeconomic position]: Parent education >high school: 79%; Married: 80%; - [underlined: Anthropometry]:; BMI percentile: 61.4 (28.4)%; BMI z-score: 0.45 (1.08); - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Chronic medical conditions or medication use affecting food intake, food allergies, BMI <5th percentile, dislike of study food | Intervention:; [underlined: Condition 1]: 100% portion size (250g, 329 kcal), lower energy density (1.32 kcal/g); [underlined: Condition 2]: 200% portion size (500g, 658 kcal), lower energy density (1.32 kcal/g); [underlined: Condition 3]: 100% portion size (250g, 460 kcal), higher energy density (1.84 kcal/g); [underlined: Condition 4]: 200% portion size (500g, 920 kcal), higher energy density (1.84 kcal/g); Children were served a macaroni and cheese entree that varied in PS and ED at a dinner meal; others foods were served in fixed portions; Duration: 1 meal (dinner) for 4 sessions; Compliance: 100% (NR); Outcomes and assessment methods: Before and after test meal; Weighed food intake | Entrée intake, total meal intake (kcal):; [underlined: Condition 1]: 217, 444; [underlined: Condition 2]: 281, 511; [underlined: Condition 3]: 282, 498; [underlined: Condition 4]: 382, 598; Portion size on entree intake and total meal energy: P<0.0001; Energy density on entree intake and total meal energy: P<0.0001; Porton size effects on energy intake did not interact with ED, P=0.32; PS and ED effects did not interact with child age, sex, ethnicity, BMI, or entree preference. | Model adjustments: NA; - Other: Entree food preference; consumption of >95% of the reference portion; Limitations:; - Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; USDA
Fisher, 2013^14^; RCT-crossover, U.S.; Baseline N=77, Analytic N=60 (Attrition: 22%); Study objective: To test effects of the amount of entree available and serving spoon size on children’s self-served entree portions and intakes at dinner meals; Participant characteristics at baseline: Children, 4-6y, English speaking; - [underlined: Age]: 59.5 (7.2) months;; Range: 48.4-72.0; - [underlined: Female]: 55%; - [underlined: Race and/or ethnicity]: White: 20%; Black: 30%; Asian: 7%; Hispanic: 43%; - [underlined: Socioeconomic position]: Parent education, high school or less: 20%; Parent employment: 50%; Participating in federally funded food assistance programs: 25%; Married: 77%; - [underlined: Anthropometry]:; BMI-for-age percentile: 59.9 (29.4)%, (Range: 48.4-72.0%); BMI-for-age z-score: 0.39 (1.11), (−2.03-3.28); - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: On a highly restrictive diet, severe food allergies, chronic illnesses or medication use affecting food intake, anticipated discomfort being away from parent during experiment, perceived and stated dislike of study foods, serving 0g of entree at >2 of 4 conditions | Intervention:; [underlined: Condition 1]: 100% (275g, 426kcal); [underlined: Condition 2]: 200% (550g, 852kcal); In 2 other conditions, children served the food using a teaspoon vs. tablespoon. Children were served an entree with fixed portions of unsweetened applesauce, baby carrots, corn, chocolate chip cookie, and 2% milk; Duration: 1 meal (dinner) once a week for 4 sessions; Compliance: Six excluded because seen in 1 or fewer trials due to dropout, child refusal, or dislike of the entree; 11 excluded for not serving any of the entree in >2 of 4 conditions; Outcomes and assessment methods: Before and after test meal; Weighed food intake | Condition 1 vs Condition 2: Energy intake from the entree, other foods, and total meal energy intake, P=NS | Model adjustments: NA; - Other: Time, portion size, serving spoon size, and entree available by spoon size interaction were all included in the model; Limitations:; - Methods for randomization and concealment NR; Did not account for the effects of those excluded due to not consuming enough study foods; No power calculation; No preregistered data analysis plan; Funding:; USDA
Fisher (children), 2007a^21^; RCT-Crossover, U.S.; Baseline N=59, Analytic N=58 (Attrition: 2%); Study objective: To examine the effects of large portions on daily energy intake in 5y old Hispanic and African American children from low-income families; Participant characteristics at baseline: Mother-child pairs, with 5y children attending Head Start; - [underlined: Age]: 5y; - [underlined: Female]: 60%; - [underlined: Race and/or ethnicity]: White: 0%; African American: 48%; Asian: 0%; Hispanic: 52%; - [underlined: Socioeconomic position]: Maternal education, HS or less: 53%; Maternal current employment: 55%; Low household food security: ~33%; - [underlined: Anthropometry]: BMI percentile: 60 (29)%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Presence of severe food allergies or chronic illnesses affecting food intake, dislike of the study foods, and self-reported previous diagnosis of maternal depression or eating disorders | Intervention:; [underlined: Condition 1]: Reference portion (100%); [underlined: Condition 2]: Large portion (200%); All foods were provided to participants. The following foods varied in portion size:; Lunch: Macaroni and cheese; Afternoon snack: Apple juice, graham crackers; Dinner: Chicken; Breakfast: Cereal; All other foods served were held constant across conditions.; Duration: 1 day (breakfast, lunch, dinner, snacks); Compliance: 1 excluded due to a loose tooth; Outcomes and assessment methods: Before and after test meals; Weighed food intake | Morning snack: No PS manipulation, P=NS between conditions; Energy intake at lunch (macaroni and cheese, kcal; all other foods, kcal):; [underlined: Condition 1]: 226 (125) kcal; 170 (95) kcal; [underlined: Condition 2]: 239 (118) kcal; 167 (86) kcal; Manipulated food: P=NS; All other foods: P=NS; Energy intake afternoon snack (apple juice, kcal; graham cracker, kcal):; [underlined: Condition 1]: 81 (37) kcal; 94 (66) kcal; [underlined: Condition 2]: 81 (59) kcal; 115 (92) kcal; Manipulated foods: P=NS for apple juice and graham crackers; Energy intake at dinner (chicken, kcal; all other foods, kcal):; [underlined: Condition 1]: 267 (96) kcal; 136 (71) kcal; [underlined: Condition 2]: 357 (143) kcal; 125 (62) kcal; Manipulated food: P<0.001; All other foods: P=NS; Evening snack: No PS manipulation, P=NS between conditions; Energy intake at breakfast (cereal, kcal; all other foods, kcal):; [underlined: Condition 1]: 108 (59) kcal; 140 (50) kcal; [underlined: Condition 2]: 163 (101) kcal; 130 (47) kcal; Manipulated food: P<0.001; All other foods: P=NS; Total energy intake:; [underlined: Condition 1]: 1500 (359) kcal; [underlined: Condition 2]: 1639 (378) kcal; P<0.001 | Model adjustments: NA; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; USDA
Keller, 2023^2^; RCT-Crossover, U.S.; Baseline N=95, Analytic N=88 (Attrition: 7%); Study objective: To determine the effects of portion size in children with lower executive functions; Participant characteristics at baseline: Children, 7-8y without obesity; - [underlined: Age]: 7.8 (0.6) y; - [underlined: Female]: 48%; - [underlined: Race and/or ethnicity]: White: 97%; NonWhite: 3%; - [underlined: Socioeconomic position]: Parent education, college or greater: 82%; Family income, $51k or greater: 88%; - [underlined: Anthropometry]: BMI percentile: 47.2 (24.6) %; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Obesity, not in good health status, not reading at grade level, developmental disorders | Intervention:; [underlined: Condition 1]: 100% portions (769 g, 1048 kcal); [underlined: Condition 2]: 133% portions (1011 g, 1377 kcal); [underlined: Condition 3]: 167% portions (1256 g, 1707 kcal); [underlined: Condition 4]: 200% portions (1492 g, 2030 kcal); Duration: 1 meal (either lunch or dinner) for 4 sessions; Compliance: Five excluded for not attending all portion size visits; Outcomes and assessment methods: Before and after test meals; Weighed food intake | Energy intake at meals:; Macaroni and cheese; [underlined: Condition 1]: 202.1(165.7) kcal; [underlined: Condition 2]: 218.9(179.1) kcal; [underlined: Condition 3]: 230.1(207.7) kcal; [underlined: Condition 4]: 223.7(196.6) kcal; Chicken nuggets; [underlined: Condition 1]: 173.6(108.2) kcal; [underlined: Condition 2]: 189.2(134.8) kcal; [underlined: Condition 3]: 228.6(187.9) kcal; [underlined: Condition 4]: 243.4(167.1) kcal; Broccoli; [underlined: Condition 1]: 30.5 (46.7) kcal; [underlined: Condition 2]: 27.1 (46.1) kcal; [underlined: Condition 3]: 28.1 (48.8) kcal; [underlined: Condition 4]: 30.6 (56.0) kcal; Grapes; [underlined: Condition 1]: 64.2 (52.2) kcal; [underlined: Condition 2]: 69.5 (58.2) kcal; [underlined: Condition 3]: 68.5 (64.2) kcal; [underlined: Condition 4]: 75.2 (68.0) kcal; Total energy intake:; [underlined: Condition 1]: 482.9 (206.9) kcal; [underlined: Condition 2]: 516.7 (222.5) kcal; [underlined: Condition 3]: 569.1 (284.8) kcal; [underlined: Condition 4]: 588.8 (252.1) kcal; Main effect for total energy intake at lunch: P<0.001; Main effect for grapes, broccoli: P=NS; Main effect for macaroni cheese, chicken nuggets: P=0.0009 | Model adjustments: NA; - Other: Familial risk status, resting energy expenditure, study visit number, pre-meal fullness, average liking rating of foods at meal; Limitations:; - Methods for randomization and concealment NR; Differences in attrition (stated sample size does not align with Figure);; Funding:; NIH, USDA
Diktas, 2022^3^; RCT-Crossover, U.S.; Baseline N=54, Analytic N=51 (Attrition: 6%); Study objective: To investigate the effect of food liking on portion selection in middle childhood and examined how children’s selections were related to measured intake at meals in which portions of all foods were varied across 4 test days; Participant characteristics at baseline: Children, 7-10y; - [underlined: Age]: 8.9 (12.) y; - [underlined: Female]: 49%; - [underlined: Race and/or ethnicity]: White: 94%; Black: 4%; Asian: 2%; - [underlined: Socioeconomic position]: Parent education, university degree: 88% of mothers, 77% of fathers; HHI > $50k: >80%; - [underlined: Anthropometry]: BMI-for-age percentile: 54.1 (28.7)%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Food allergies, taking medications that might influence appetite | Intervention:; [underlined: Condition 1]: 100% portions (630 g); [underlined: Condition 2]: 133% portions (840 g); [underlined: Condition 3]: 167% portions (1050 g); [underlined: Condition 4]: 200% portions (1260 g); Duration: 1 meal (lunch) for 4 sessions; Compliance: One excluded for highly variable data; Outcomes and assessment methods: Before and after the test meal; Weighed food intake | Energy intake from cherry tomatoes, kcal (100%, 133%, 167%, 200%):; 3 (1), 2 (1), 3(1), 3 (1); Energy intake from broccoli, kcal (100%, 133%, 167%, 200%):; 20 (2), 21 (3), 26 (3), 24 (4); Energy intake from grapes, kcal (100%, 133%, 167%, 200%):; 53 (3), 60 (4), 71 (6), 71 (6); Energy intake from macaroni and cheese, kcal (100%, 133%, 167%, 200%):; 224 (22), 268 (27), 261 (30), 245 (31); Energy intake from angel food cake, kcal (100%, 133%, 167%, 200%):; 68 (6), 82 (7), 89 (9), 89 (11); Energy intake from garlic bread, kcal (100%, 133%, 167%, 200%):; 168 (9), 208 (12), 245 (16), 256 (19), P=NR; Main effect of portion size across all foods compared to baseline: P<0.0001; Total energy intake at lunch:; Condition 1 (100%): 536 (28) kcal; Condition 2 (133%): 641 (35) kcal; Condition 3 (167%): 695 (37) kcal; Condition 4 (200%): 689 (41) kcal; P=0.003 | Model adjustments: NA; Limitations:; - Randomization and concealment methods NR; Did not clearly report statistical significance between conditions for energy intake; Funding:; NIH, Penn State
Kral, 2014^13^; RCT-Crossover, U.S.; Baseline N=59, Analytic N=50 (Attrition: 15%); Study objective: To determine if children’s weight status and relative reinforcing value of food interact with portion size to affect intake; Participant characteristics at baseline: Children, 8-10y who were normal weight or obese; - [underlined: Age]: 9.6 (0.8) y; - [underlined: Female]: 52%; - [underlined: Race and/or ethnicity]: White: 22%; Black or African American: 68%; More than one race: 10%; Hispanic: 8%;; Not Hispanic: 82%; Unknown: 10%; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]:; BMI: 20.8 (1.8) kg/m^2^; BMI z-score: 0.9 (0.5); BMI-for-age percentile: 71.8% (13.1); - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Did not like study foods, had medical conditions or were taking medications known to affect food intake or body weight, were diagnosed with a learning disability or sight/hearing impairment, had food allergies/intolerances, or were on a special diet. | Intervention:; [underlined: Condition 1]: 100% portion size, 1,563 kcal; [underlined: Condition 2]: 150% portion size, 2,345 kcal; [underlined: Condition 3]: 200% portion size, 3,126 kcal; Duration: 1 meal (dinner) for 3 sessions; Compliance: Eight were used as pilot subjects to determine food and beverage portion size; 1 was excluded due to medical diagnosis and starting medication while participating in study.; Outcomes and assessment methods: Before and after the test meal; Weighed food intake | Total energy intake at dinner:; [underlined: Condition 1]: 921 (40) kcal; [underlined: Condition 2]: 1046 (41) kcal; [underlined: Condition 3]: 1041 (40) kcal; P=0.003 | Model adjustments: NA; Limitations:; - Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; NIH
Aerts (Study 1), 2017^1^; RCT-Parallel, Belgium; Baseline N=96, Analytic N=96 (Attrition: 0%); Study objective: To determine the effect of increasing portion size on intake in children, and to determine whether the effect varies depending on type of food; Participant characteristics at baseline: Children, ages 6-7y; - [underlined: Age]: 6.43 (0.68) y; - [underlined: Female]: 48%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]:; BMI: 16 (1.84) kg/m^2^;; Overweight: 14.5%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: No parental consent; allergies; did not like popcorn | Intervention:; [underlined: Group 1]: 100%, 30 g, 124 kcal, sugared popcorn; [underlined: Group 2]: 100%, 30 g, 118 kcal, salted popcorn; [underlined: Group 3]: 200%, 60 g, 247 kcal, sugared popcorn; [underlined: Group 4]: 200%, 60 g, 235 kcal, salted popcorn; Duration: 1 meal (snack) for 4 sessions; Compliance: NR; Outcomes and assessment methods: Before and after test meal; Weighed food intake | Energy intake (kcal):; [underlined: Group 1]: 112 (31) kcal; [underlined: Group 2]: 94 (40) kcal; [underlined: Group 3]: 233 (50) kcal [underlined: Group 4]: 167 (47) kcal; Portion size: P<0.01 (Group 1, 2 vs Group 3, 4 (100% vs 200%): 26.45 (9.01) g vs 51.21 (13.79) g, P<0.01); Popcorn type: P<0.01; Portion size vs popcorn type: P=0.02 | Model adjustments: NA; Limitations:; - Methods for randomization and concealment NR; Weighing prior to eating may have influenced intake; Almost all children consumed popcorn; No power calculation; No preregistered data analysis plan; Funding:; NR
Aerts (Study 2), 2017^1^; RCT-Crossover, Belgium; Baseline N=61, Analytic N=55 (Attrition: 10%); Study objective: To determine the effect of increasing portion size on intake in children, and to determine whether the effect varies depending on type of food; Participant characteristics at baseline: Children, ages 3-6y; - [underlined: Age]: 4.67 (0.86) y; - [underlined: Female]: 47%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: NR; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: No parental consent, did not like or were allergic to study foods, illness, unusable data | Intervention:; [underlined: Condition 1]: 100% carrots, 80 g carrots, 28 kcal; [underlined: Condition 2]: 160% carrots, 130 g carrots, 46 kcal; [underlined: Condition 3]: 100% cookies, 30 g cookies, 120 kcal; [underlined: Condition 4]: 160% cookies, 48 g, 192 kcal; Duration: 1 meal (snack) for 4 sessions; Compliance: Four excluded for allergy or disliking of study foods, 2 excluded for illness; Outcomes and assessment methods: Before and after test meal; Weighed food intake | Energy intake (kcal):; [underlined: Condition 1]: 15 (10) kcal; [underlined: Condition 2]: 17 (14) kcal; [underlined: Condition 3]: 102 (34) kcal; [underlined: Condition 4]: 131 (63) kcal; Portion size: P<0.01 for cookies; P=NS for carrots; Food type: P<0.01; Portion size vs food type: P<0.01 | Model adjustments: NA; Limitations:; - Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; NR

a Abbreviations: RCT: Randomized Controlled Trial; y: years; BMI: Body Mass Index; kg/m2: Kilograms per meters squared; SD: Standard Deviation; NR: Not Reported; TEI: Total Energy Intake; g: gram; Kcal: kilocalorie; kcal/g: kilocalories per gram; fl. oz: Fluid ounce; NA: Not applicable; NIH: National Institutes of Health; NS: Not significant; R&D: Research and development; PS: Portion size; ED: Energy density; HED: High energy dense; LED: Low energy dense; HHI: Household income; U.S: United States; U.K.: United Kingdom; BBSRC: Biotechnology and biological sciences research council; £: U.K. pound; USDA: United States Department of Agriculture; 50k: $50,000; CACFP: Child and Adult Care Food Program; NRCT: non-randomized controlled trial; FVs: Fruits and vegetables

Table 16 Risk of bias for randomized controlled trials examining portion size and energy intake in young children, children, and adolescents^*^ * Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Article | Randomization | Period and carryover effects | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Fisher, 2007c ^23^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Huss, 2013 ^4^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Rolls, 2000 ^25^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Looney, 2011 ^18^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Carstairs, 2018 ^8^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Norton, 2015 ^11^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Reale, 2018 ^26^ | SOME CONCERNS | NOT APPLICABLE | HIGH | LOW | HIGH | LOW | HIGH
Orlet Fisher, 2003 ^24^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Kling, 2016a ^9^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Diktas, 2021 ^6^ | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Savage, 2012 ^16^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Kling, 2016b ^10^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Spill, 2010 ^19^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Smethers, 2019 ^7^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Roe, 2022 ^5^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Spill, 2011 ^17^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Mathias, 2012 ^15^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Mooreville, 2015 ^12^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Kral, 2010 ^20^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Fisher, 2007b ^22^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Fisher, 2013 ^14^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Fisher, 2007a ^21^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Keller, 2023 ^2^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Diktas, 2022 ^3^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Kral, 2014 ^13^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Aerts, 2017 (study 1) ^1^ | SOME CONCERNS | NOT APPLICABLE | HIGH | LOW | HIGH | LOW | HIGH
Aerts, 2017 (study 2) ^1^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

Table 17 Risk of bias for non-randomized controlled trials examining portion size energy intake in young children, children, and adolescents^*^ * Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool (https://www.riskofbias.info/welcome/home/current-version-of-robins-i)” ( Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919. doi: 10.1136/bmj.i4919.27733354 )

Article | Confounding | Selection of participants | Classifications of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
McCrickerd, 2017 ^27^ | SERIOUS | LOW | LOW | SERIOUS | LOW | LOW | LOW | SERIOUS

Table 18 Evidence examining the relationship between portion size and energy intake in adults and older adults^a^

Study and Population Characteristics | Intervention, Comparator, and Outcomes | Results | Confounding and Study Limitations
Haynes (Study 1), 2020a^29^; RCT-Crossover, U.K.; Baseline N=49, Analytic N=45 (Attrition: 8%); Study objective: To test whether portion size effects on intake would be impacted if the resulting portion size was no longer visually perceived as ‘normal’; Participant characteristics at baseline:; Adults, BMI between 22.5-32.5 kg/m^2^; - [underlined: Age]: 30.4 (12.7) y (18–76y); - [underlined: Female]: 51%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 26.9 (3.7) kg/m^2^ (18.9-35.3); - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Food allergies or intolerances, specific dietary requirements, history of eating disorders, did not like or not willing to consume test foods | Intervention:; [underlined: Condition 1]:; Large normal (120%, 336 g, 307 kcal); [underlined: Condition 2]:; Small normal (90%, 252 g, 230 kcal); [underlined: Condition 3]:; Smaller than normal (60%, 168 g, 154 kcal); A bowl of extra pasta (200%) was provided to allow for refills if desired; Duration: 1 meal (lunch) per 3 conditions; Compliance: One excluded due to scheduling conflict, 2 excluded due to an error in portion served, 1 excluded due to high BMI; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Energy intake (kcal) from the initial entree:; Condition 1 vs Condition 3: 136 (5) kcal, P<0.001; Condition 2 vs Condition 3: 72 (2) kcal, P<0.001; Condition 1 vs Condition 2: 64 (4) kcal, P<0.001; Energy intake (kcal) from the additional entree:; Condition 1 vs Condition 3: 59 (12) kcal, P<0.001; Condition 2 vs Condition 3: 38 (12) kcal, P=0.002; Condition 1 vs Condition 2: 21 (12) kcal, P=0.08; Energy intake (kcal) from total meal:; Condition 1 vs Condition 3: 77 (12) kcal, P<0.001; Condition 2 vs Condition 3: 34 (11) kcal, P=0.01; Condition 1 vs Condition 2: 43 (12) kcal, P=0.001 | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization concealment NR; No preregistered data analysis plan (for study 1); Funding:; Medical Research Council
Haynes (Study 2), 2020a^29^; RCT-Crossover, U.K.; Baseline N=41, Analytic N=37 (Attrition: 10%); Study objective: To test whether portion size effects on intake would be impacted if the resulting portion size was no longer visually perceived as ‘normal’; Participant characteristics at baseline:; Adults, BMI between 22.5-32.5 kg/m^2^; - [underlined: Age]: 32.2 (12.2) y (20-59y); - [underlined: Female]: 51%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 26.9 (3.7) kg/m^2^ (20.1-35.5); - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Food allergies or intolerances, specific dietary requirements, history of eating disorders, did not like or not willing to consume test foods | Intervention:; [underlined: Condition 1]:; Large normal (130%, 423 g, 506 kcal); [underlined: Condition 2]:; Small normal (100%, 325 g, 389 kcal); [underlined: Condition 3]:; Smaller than normal (70% 228 g, 272 kcal); A dessert buffet was provided, and participants were allowed to self-serve dessert if desired; Duration: 1 meal (lunch) per 3 conditions; Compliance: 1 excluded due to scheduling conflict, 2 excluded due to an error in portion served; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Energy intake (kcal) from the initial entree:; Condition 1 vs Condition 3: 188 (13) kcal, P<0.001; Condition 2 vs Condition 3: 101 (7) kcal, P<0.001; Condition 1 vs Condition 2: 87 (8) kcal, P<0.001; Energy intake (kcal) from the dessert buffet:; Condition 1 vs Condition 3: 56 (20) kcal, P=0.01; Condition 2 vs Condition 3: 36 (18) kcal, P=0.06; Condition 1 vs Condition 2: 20 (17) kcal, P=0.26; Energy intake (kcal) from the total meal:; Condition 1 vs Condition 3: 132 (22) kcal, P<0.001; Condition 2 vs Condition 3: 66 (19) kcal, P=0.001; Condition 1 vs Condition 2: 67 (21) kcal, P=0.003 | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization concealment NR; Funding:; Medical Research Council
Gough (Study 1), 2021^30^; RCT-Parallel, U.K.; Baseline N=68, Analytic N=60 (Attrition: 12%); Study objective: To compare the influence of portion size on snack food intake when food intake was examined in a standard laboratory setting vs. at home; Participant characteristics at baseline:; Adults, 18 y and older, afternoon snack consumers; - [underlined: Age]: ~32 (11) y; - [underlined: Female]: 73%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: ~24 (4) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting, don’t like study foods, no history of food allergies or intolerances | Intervention:; [underlined: Group 1]: 100% (100 g, 526 kcal); laboratory vs. home setting; [underlined: Group 2]: 200% (200 g, 1052 kcal); laboratory vs. home setting; Portion size was a between subjects comparison; the study also included a within subjects comparison of consuming a snack in a laboratory vs. naturalistic setting; Duration: 1 meal (snack); Compliance: Four excluded for missing a session, 4 excluded for dieting at the end of the study; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Energy intake (kcal):; Participants served the larger PS (200%) consumed significantly more kcal than those served the smaller PS (100%), P=0.001 (Data not reported; figure only) | Model adjustments:; - TEI: NR; Limitations:; - No preregistered data analysis plan; Funding:; Medical Research Council; Wellcome Trust; British Psychological Society
Gough (Study 2), 2021^30^; RCT-Parallel, U.K.; Baseline N=65, Analytic N=59 (Attrition: 9%); Study objective: To examine the effects of portion size of snack food intake in a standard laboratory setting vs. semi-naturalistic laboratory setting designed to resemble a lounge (home) setting; similar to study 1, but with sex of participants equally distributed; Participant characteristics at baseline:; Adults, 18 y and older, afternoon snack consumers; - [underlined: Age]: ~28 (8) y; - [underlined: Female]: 66%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: ~24 (6) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting, did not like study foods, no history of food allergies or intolerances; participants from study 1; anyone based in the same building as the labs | Intervention:; [underlined: Group 1]: 100% (100 g, 526 kcal); laboratory vs. semi-naturalistic setting; [underlined: Group 2]: 200% (200 g, 1052 kcal); laboratory vs. semi-naturalistic setting; Portion size was a between subjects comparison; the study also included a within subjects comparison of consuming a snack in a laboratory vs. naturalistic setting; Duration: 1 meal (snack); Compliance: One excluded for missing a session, 5 excluded for dieting at the end of the study; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Energy intake (kcal):; Participants served the larger PS (200%) consumed significantly more kcal than those served the smaller PS (100%), P=0.05 (Data not reported; figure only) | Model adjustments:; - TEI: NR; Limitations:; - No preregistered data analysis plan; Funding:; Medical Research Council; Wellcome Trust; British Psychological Society
Cunningham (Experiment 1), 2023b^31^; RCT-Crossover, U.S.; Baseline N=43, Analytic N=42 (Attrition: 2%); Study objective: To determine the effect of serving meals with high variety or large portions on food intake compared to meals with low variety or small portions, at meals with a simultaneous structure; Participant characteristics at baseline:; Women, 20-65 y; - [underlined: Age]: 39 (13) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: White: 71%; Asian: 19%; Multiple races: 7%; Hispanic: 7%; - [underlined: Socioeconomic position]: University degree: 90%; HHI >$50k: 79%; - [underlined: Anthropometry]: BMI: 24.9 (4.3) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Males, do not regularly eat 3 meals a day, unwilling to eat the study food, unwilling to refrain from drinking alcohol the day before study meals, currently dieting, smokers, athletes in training, taking medications or reported a health condition known to affect appetite, pregnant or breastfeeding, allergies or intolerances to the food served, religious or other restrictions to the food served, ever been diagnosed with an eating disorder or depression, or specialized in the fields of Psychology or Nutritional Sciences, participants with a low liking for any of the study foods or who had high variability in their liking of study foods, BMI <18.5 or >35.0 kg/m^2^ | Intervention:; [underlined: Condition 1]:; Small portion (450 g), Low variety (1 entrée); [underlined: Condition 2]:; Small portion (450 g), High variety (3 entrées served simultaneously); [underlined: Condition 3]:; Large portion (600 g), Low variety (1 entrée); [underlined: Condition 4]:; Large portion (600 g), High variety (3 entrée served simultaneously); Entrees were shrimp teriyaki, chicken alfredo, and southwestern rice. All had an energy density of 1.3 kcal/g.; In the low variety conditions, subjects were served their preferred entree; Duration: 1 meal (lunch) for 4 sessions; Compliance: One excluded after withdrawing for personal reasons; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Entree intake at lunch:; [underlined: Condition 1]: 358 (26) kcal; [underlined: Condition 2]: NR; [underlined: Condition 3]: NR; [underlined: Condition 4]: 452 (26) kcal; Portion size effect, Large vs small portion: 76 (11) kcal, P<0.0001; Variety effect, High vs low variety: 19 (11) kcal, P=0.03; Portion size and variety interaction: P=NS | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization concealment NR; Funding:; Jenny Craig, Inc
Cunningham (Experiment 2), 2023b^31^; RCT-Crossover, U.S.; Baseline N=52, Analytic N=49 (Attrition: 6%); Study objective: To determine the effect of serving meals with high variety or large portions on food intake compared to meals with low variety or small portions, at meals with a sequential structure; Participant characteristics at baseline:; Women, 20-65 y; - [underlined: Age]: 36 (15) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: White: 71%; Asian: 24%; Multiple races: 4%; Hispanic: 2%; - [underlined: Socioeconomic position]: University degree: 96%; HHI >$50k: 80%; - [underlined: Anthropometry]: BMI: 24.3 (3.8) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Males, do not regularly eat 3 meals a day, unwilling to eat the study food, unwilling to refrain from drinking alcohol the day before study meals, currently dieting, smokers, athletes in training, taking medications or reported a health condition known to affect appetite, pregnant or breastfeeding, allergies or intolerances to the food served, religious or other restrictions to the food served, ever been diagnosed with an eating disorder or depression, or specialized in the fields of Psychology or Nutritional Sciences, participants with a low liking for any of the study foods or who had high variability in their liking of study foods, BMI <18.5 or >35.0 kg/m^2^, those who took part in experiment 1 | Intervention:; [underlined: Condition 1]:; Small portion (450 g), Low variety (1 entrée); [underlined: Condition 2]:; Small portion (450 g), High variety (3 entrée served sequentially); [underlined: Condition 3]:; Large portion (600 g), Low variety (1 entrée); [underlined: Condition 4]:; Large portion (600 g), High variety (3 entrée served sequentially); Entrees were shrimp teriyaki, chicken alfredo, and southwestern rice. All had an energy density of 1.3 kcal/g.; In the low variety conditions, subjects were served their preferred entree; Duration: 1 meal (lunch) for 4 sessions; Compliance: Two were excluded after withdrawing for personal reasons, and 1 withdrew due to pregnancy; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Entree intake at lunch:; [underlined: Condition 1]: 385 (22) kcal; [underlined: Condition 2]: NR; [underlined: Condition 3]: NR; [underlined: Condition 4]: 490 (22) kcal; Portion size effect, Large vs small portion: 66 (11) kcal, P<0.0001; Variety effect, High vs low variety: 39 (11) kcal, P<0.001; Portion size and variety interaction: P=NS | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization concealment NR; Funding:; Jenny Craig, Inc
Robinson (Experiment 1), 2018^32^; RCT-Parallel, U.K.; Baseline N=84, Analytic N=75 (Attrition: 11%); Study objective: To test whether reducing a food portion size “renormalizes” perceptions of what constitutes a normal amount of that food to eat and results in people selecting and consuming smaller portions of that food in the future; Participant characteristics at baseline:; University staff and students; - [underlined: Age]: 31.9 (9.4) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 24.7 (4.8) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Food allergies, dieting for weight loss; did not like study food | Intervention:; Day 1:; [underlined: Group 1]: 100%, 100g, 220 kcal; [underlined: Group 2]: 200%, 200g, 440 kcal; Day 2:; Full family-sized quiche, 400g, 880 kcal; On day 1, subjects were served a meal, and on day 2 they self-served; Duration: 1 meal (lunch) on 2 consecutive days; Compliance: Four excluded for guessing the study purpose, 4 excluded for not attending one session, 1 excluded for not following protocol; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Entrée intake (kcal); [underlined: Group 1]: 218 (21) kcal; [underlined: Group 2]: 388 (58) kcal; P<0.001; Day 2, Entree intake (kcal); [underlined: Group 1]: 318 (159) kcal; [underlined: Group 2]: 418 (122) kcal; P=0.003; Intake of other foods:; Group 1 vs Group 2: Salad intake did not significantly differ, P=NS | Model adjustments:; - TEI: NR; Limitations:; - Randomization concealment NR; Did not account for those lost to follow-up; Funding:; Medical Research Council and Economic Social Research Council
Robinson (Experiment 2), 2018^32^; RCT-Parallel, U.K.; Baseline N=83, Analytic N=78 (Attrition: 6%); Study objective: To test whether reducing a food portion size “renormalizes” perceptions of what constitutes a normal amount of that food to eat and results in people selecting and consuming smaller portions of that food in the future; Participant characteristics at baseline:; University staff and students; - [underlined: Age]: 24.5 (7.0) y; - [underlined: Female]: 0%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 25.2 (4.5) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Food allergies, dieting for weight loss | Intervention:; Day 1; [underlined: Group 1]: 100%, 100g, 220 kcal; [underlined: Group 2]: 200%, 200g, 440 kcal; Day 2; Full family-sized quiche, 400g, 880 kcal; On day 1, subjects were served a meal, and on day 2 they self-served; Duration: 1 meal (lunch) on 2 consecutive days; Compliance: Two excluded for guessing the study purpose, 3 excluded for not following protocol; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Entrée intake (kcal); [underlined: Group 1]: 219 (25) kcal; [underlined: Group 2]: 429 (33) kcal; P<0.001; Intake of other foods:; Group 1 vs Group 2: 57.2 (6.3)g vs 51.5 (14.8), P=0.03; Group 1 vs Group 2: Potato chip intake did not significantly differ, P=NS; Day 2:; [underlined: Group 1]: 333 (172) kcal; [underlined: Group 2]: 540 (177) kcal; P<0.001 | Model adjustments:; - TEI: NR; Limitations:; - Randomization concealment NR; Did not account for those lost to follow-up; Funding:; Medical Research Council and Economic Social Research Council
Robinson (Experiment 3), 2018^32^; RCT-Parallel, U.K.; Baseline N=140, Analytic N=124 (Attrition: 11%); Study objective: To test whether reducing a food portion size “renormalizes” perceptions of what constitutes a normal amount of that food to eat and results in people selecting and consuming smaller portions of that food in the future; Participant characteristics at baseline:; University staff and students; - [underlined: Age]: 27.7 (9.6) y; - [underlined: Female]: 63%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 23.6 (4.1) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Food allergies, dieting for weight loss | Intervention:; [underlined: Group 1]: 100%, 100g, 279 kcal; [underlined: Group 2]: 200%, 200g, 558 kcal; Duration: 1 meal (lunch); Compliance: Three excluded for not completing study questionnaires, 1 excluded for guessing the study purpose, 12 excluded for not following study protocol; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Entrée intake (kcal); [underlined: Group 1]: 272 (36) kcal; [underlined: Group 2]: 501 (89) kcal; P<0.001; Intake of other foods:; Group 1 vs Group 2: Salad intake did not significantly differ, P=NS; Group 1 vs Group 2: Potato chip intake did not significantly differ, P=NS | Model adjustments:; - TEI: NR; Limitations:; - Randomization concealment NR; Did not account for those lost to follow-up; Funding:; Medical Research Council and Economic Social Research Council
Rolls (Experiment 1: Addition study), 2010^33^; RCT-Crossover, U.S.; Baseline N=52, Analytic N=49 (Attrition: 6%); Study objective: To test the effects of increasing vegetable portion size and energy density, without changing the other meal foods; Participant characteristics at baseline:; Adults, age 20-45y, BMI between 18-40 kg/m^2^, regularly ate 3 meals; - [underlined: Age]: 26.8 (2.8) y; - [underlined: Female]: 49%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 24.1 (0.6) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting, food allergies or restrictions, medications that affect appetite, smokers, athletes, pregnant or breastfeeding, disliked study foods, scored high on depression scale, scored high for disordered eating | Intervention:; [underlined: Condition 1]: 180g broccoli, 0.4 kcal/g; [underlined: Condition 2]: 180g broccoli, 0.8 kcal/g; [underlined: Condition 3]: 270g broccoli, 0.4 kcal/g; [underlined: Condition 4]: 270g broccoli, 0.8 kcal/g; [underlined: Condition 5]: 360g broccoli, 0.4 kcal/g; [underlined: Condition 6]: 360g broccoli, 0.8 kcal/g; ED was increased by adding butter; all meals were served with the same amount of rice and meat (pot roast); Duration: 1 meal (lunch) for 6 weeks; Compliance: One participant was excluded for non-compliance; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Total meal energy intake, kcal; [underlined: Condition 1]: 555 (32) kcal; [underlined: Condition 2]: 592 (34) kcal; [underlined: Condition 3]: 541 (35) kcal; [underlined: Condition 4]: 616 (35) kcal; [underlined: Condition 5]: 574 (34) kcal; [underlined: Condition 6]: 631 (38) kcal; PS effect: NS; ED effect: P<0.0001; Vegetable intake, kcal; [underlined: Condition 1]: 48.4 (3.2) kcal; [underlined: Condition 2]: 101.6 (5.6) kcal; [underlined: Condition 3]: 59.6 (4) kcal; [underlined: Condition 4]: 128 (8) kcal; [underlined: Condition 5]: 69.2 (4.8) kcal; [underlined: Condition 6]: 151.2 (10.4) kcal; PS effect: P<0.0001; ED effect: P<0.007 | Model adjustments: NA; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; NIH
Rolls (Experiment 2: Substitution study), 2010^33^; RCT-Crossover, U.S.; Baseline N=48, Analytic N=48 (Attrition: 0%); Study objective: To test the effects of increasing vegetable portion size and energy density, while decreasing the portion sizes of other meal components served; Participant characteristics at baseline:; Adults, age 20-45y, BMI between 18-40 kg/m^2^, regularly ate 3 meals; - [underlined: Age]: 26.7 (1.4) y; - [underlined: Female]: 50%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 23.6 (0.6) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting, food allergies or restrictions, medications that affect appetite, smokers, athletes, pregnant or breastfeeding, disliked study foods, scored high on depression scale, scored high for disordered eating | Intervention:; [underlined: Condition 1]:; 180g broccoli, 0.4 kcal/g, 326g rice, 281g meat; [underlined: Condition 2]:; 180g broccoli, 0.8 kcal/g, 326g rice, 281g meat; [underlined: Condition 3]:; 270g broccoli, 0.4 kcal/g, 272g rice, 234g meat; [underlined: Condition 4]:; 270g broccoli, 0.8 kcal/g, 272g rice, 234g meat; [underlined: Condition 5]:; 360g broccoli, 0.4 kcal/g, 217g rice, 187g meat; [underlined: Condition 6]:; 360g broccoli, 0.8 kcal/g, 217g rice, 187g meat; ED was increased by adding butter; as proportion of vegetable was increased from 25% to 38% or 50% of the plate, the proportions of the grain and meat were decreased from 38% to 31% to 25% of the plate.; Duration: 1 meal (lunch) for 6 weeks; Compliance: 100% compliance; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Total meal energy intake, kcal; [underlined: Condition 1]: 514 (27) kcal; [underlined: Condition 2]: 552 (26) kcal; [underlined: Condition 3]: 469 (24) kcal; [underlined: Condition 4]: 517 (26) kcal; [underlined: Condition 5]: 466 (22) kcal; [underlined: Condition 6]: 537 (24) kcal; PS effect: P<0.0001; ED effect: P<0.0001; Vegetable intake, kcal; [underlined: Condition 1]: 53.2 (2.8) kcal; [underlined: Condition 2]: 107.2 (5.6) kcal; [underlined: Condition 3]: 67.2 (4.4) kcal; [underlined: Condition 4]: 138.4 (8.8) kcal; [underlined: Condition 5]: 76 (4.8) kcal; [underlined: Condition 6]: 164 (10.4) kcal; PS effect: P<0.0001; ED effect: NS | Model adjustments: NA; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; NIH
Berkowitz, 2016^34^; NRCT, U.S.; Baseline N=, Analytic N=521 (Baseline) 603 (Intervention) (Attrition: 0%); Study objective: To determine whether customers in two different food-service operator segments (non-commercial worksite cafeteria and commercial upscale restaurant) would select reduced-portion menu items and the impact of selecting reduced-portion menu items on energy and nutrient intakes; Participant characteristics at baseline:; Employees of a worksite cafeteria; - [underlined: Age]: NR; - [underlined: Female]: NR; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: NR; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: NR | Intervention:; [underlined: Baseline]: Full-size entrees; [underlined: Intervention]: Full and reduced-size entrees; Duration: 12 weeks (lunch): 5-week baseline; 7-week intervention; Compliance: NR; Outcomes and assessment methods: Weighed plate waste subtracted from the average serving weight; Calories derived from recipes provided by restaurant manager. After meals | Energy intake (kcal, mean (SE)):; [underlined: Baseline]: 629 (4.4) kcal; [underlined: Intervention]: 555 (5.2) kcal; p<0.0001 | Model adjustments:; - TEI: NR; - Key confounders: Did not account for key confounders; - Other: NA; Limitations:; - Did not account for any key confounders; Did not describe participant selection; Outcome assessment was based on average serving size and recipes, which could be prone to error; Pricing was also manipulated and not accounted for; Unclear how side dishes or other foods ordered were accounted for; No preregistered data analysis plan; Funding:; University of Minnesota; NIFA
Berkowitz, 2016^34^; NRCT, U.S.; Baseline N=, Analytic N=90 (Baseline) 95 (Intervention) (Attrition: 0%); Study objective: To determine whether customers in two different food-service operator segments (non-commercial worksite cafeteria and commercial upscale restaurant) would select reduced-portion menu items and the impact of selecting reduced-portion menu items on energy and nutrient intakes; Participant characteristics at baseline:; Diners of a private golf club; - [underlined: Age]: NR; - [underlined: Female]: NR; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: NR; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: NR | Intervention:; [underlined: Baseline]: Full-size entrees; [underlined: Intervention]: Full and reduced-size entrees; Duration: 7 weeks (dinner): 3-week baseline; 4-week intervention; Compliance: NR; Outcomes and assessment methods: Weighed plate waste subtracted from the average serving weight; Calories derived from recipes provided by chef. After meals | Energy intake (kcal, mean (SE)):; [underlined: Baseline]: 695 (24.4) kcal; [underlined: Intervention]: 393 (14.3) kcal; p<0.0001 | Model adjustments:; - TEI: NR; - Key confounders: Did not account for key confounders; Limitations:; - Did not account for any key confounders; Did not describe participant selection; Outcome assessment was based on average serving size and recipes, which could be prone to error; Pricing was also manipulated and not accounted for; Unclear how side dishes or other foods ordered were accounted for; No preregistered data analysis plan; Funding:; University of Minnesota; NIFA
Langfield (Study 1), 2023^35^; RCT-Crossover, U.K.; Baseline N=61, Analytic N=50 (Attrition: 18%); Study objective: To test the effect of reducing food portion sizes on daily energy intake and determine if it differs based on SEP; Participant characteristics at baseline:; Adults, women, age 18 and older, BMI 18.5-32.5 kg/m^2^, with either high or low socioeconomic position; - [underlined: Age]: 42.3 (19.4) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: White: 84%; Black, African, Caribbean, or Black British: 2%; Asian or Asian British: 12%; Mixed or multiple: 2%; - [underlined: Socioeconomic position]: Recruitment was stratified by highest educational qualification, lower (A-levels or less) and higher (higher education/degree level) Years in higher education: 3.00 (2.96); Years in higher education, mean: 3y; HHI: 17k (13k) pounds; Subjective social status, mean: 5.5 (1.4); - [underlined: Anthropometry]: BMI: 25.8 (3) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dietary restrictions including being vegetarian or dieting, food allergies, self-reported dislike of the test foods, history of eating disorders, on medication affecting appetite, pregnant, could not participate in study 2 | Intervention:; [underlined: Condition 1]: 100%, all foods served at lunch (375 g, 544 kcal) and dinner (291 g, 339 kcal), 6328 kcal; [underlined: Condition 2]: 150%, all foods served at lunch (563 g, 816 kcal) and dinner (437 g, 509 kcal), 6770 kcal; Duration: 2 meals (lunch, dinner) for 2 sessions; Compliance: Five excluded for withdrawing before study started, 6 excluded for not following the protocol or missing a session; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Total daily energy intake:; Higher SEP; [underlined: Condition 1]: 2517.44 (641.12) kcal; [underlined: Condition 2]: 2724.83 (711.90); Lower SEP; [underlined: Condition 1]: 2063.59 (397.32) kcal; [underlined: Condition 2]: 2326.05 (509.51) kcal; Main effect portion size: P<0.001; Main effect SEP: P=0.009; Portion size, SEP interaction: P=NS; Energy intake from portion manipulated foods:; Higher SEP; [underlined: Condition 1]: 794.61 (98.81) kcal; [underlined: Condition 2]: 1074.74 (225.58) kcal; Lower SEP; [underlined: Condition 1]: 813.08 (84.30) kcal; [underlined: Condition 2]: 1030.80 (187.18) kcal; Main effect portion size: P<0.001; Main effect SEP: P=NS; Portion size, SEP interaction: P=NS; Energy intake from non-portion manipulated foods:; Higher SEP; [underlined: Condition 1]: 1722.8 (595.17) kcal; [underlined: Condition 2]: 1650.10 (631.66) kcal; Lower SEP; [underlined: Condition 1]: 1250.5 (361.19) kcal; [underlined: Condition 2]: 1295.24 (403.65) kcal; Main effect portion size: P=NS; Main effect SEP: P=0.004; Portion size, SEP interaction: P=NS | Model adjustments:; - TEI: NR; Limitations:; - None identified; Funding:; European Research Council
Langfield (Study 2), 2023^35^; RCT-Crossover, U.K.; Baseline N=50, Analytic N=46 (Attrition: 8%); Study objective: To test the effect of reducing food portion sizes on daily energy intake and determine if it differs based on SEP; Participant characteristics at baseline:; Adults, women, age 18 and older, BMI 18.5-39.9 kg/m^2^, with either high or low socioeconomic position; - [underlined: Age]: 51.6 (15.6 ) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: White: 94%; Black, African, Caribbean, or Black British: 2%; Asian or Asian British: 2%; Mixed or multiple: 2%; - [underlined: Socioeconomic position]: Years in higher education, mean: 3.11 (2.46); HHI: 20k (13k) pounds; Recruitment was stratified by subjective social status, lower (scores of 1-4) and higher 6-10); Subjective social status, mean: 5; - [underlined: Anthropometry]: BMI: 28 (5) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Medium socioeconomic position, dietary restrictions (except for vegetarians) or dieting, food allergies, self-reported dislike of the test foods, history of eating disorders, on medication affecting appetite, pregnant; could not participate in study 1 | Intervention:; [underlined: Condition 1]: 100%, all foods served at breakfast (290 g, 591 kcal), lunch (350 g, 508 kcal), and dinner (291 g, 296 kcal), 5040 kcal; [underlined: Condition 2]: 150%, all foods served at breakfast (435 g, 887 kcal), lunch (525 g, 761 kcal), and dinner (437 g, 444 kcal), 5643 kcal; Duration: 1 day (breakfast, lunch, dinner) for 2 sessions; Compliance: Two excluded for withdrawing before study started, 2 excluded for not following the protocol or missing a session; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Total daily energy intake:; Higher SEP; [underlined: Condition 1]: 2009.261 (438.11) kcal; [underlined: Condition 2]: 2099.951 (2099.95) kcal; Lower SEP; [underlined: Condition 1]: 1935.548 (427.29) kcal; [underlined: Condition 2]: 2131.757 (506.51) kcal; Main effect portion size: P=0.02; Main effect SEP: P=NS; Portion size, SEP interaction: P=NS; Energy intake from portion manipulated foods:; Higher SEP; [underlined: Condition 1]: 1013.52 (199.64) kcal; [underlined: Condition 2]: 1179.53 (262.32) kcal; Lower SEP; [underlined: Condition 1]: 993.91 (176.28) kcal; [underlined: Condition 2]: 1230.96 (271.99) kcal; Main effect portion size: P<0.001; Main effect SEP: P=NS; Portion size, SEP interaction: P=NS; Energy intake from non-portion manipulated foods:; Higher SEP; [underlined: Condition 1]: 995.74 (315.87) kcal; [underlined: Condition 2]:920.42 (246.31) kcal; Lower SEP; [underlined: Condition 1]: 941.63 (375.63) kcal; [underlined: Condition 2]: 900.79 (390.97) kcal; Main effect portion size: P=NS; Main effect SEP: P=NS; Portion size, SEP interaction: P=NS | Model adjustments:; - TEI: NR; Limitations:; - None identified; Funding:; European Research Council
Rolls, 2004b^36^; RCT-Crossover, U.S.; Baseline N=76, Analytic N=75 (Attrition: 1%); Study objective: To investigate the effect on energy intake of increasing the portion size of a food served as a discrete unit.; Participant characteristics at baseline:; Adults, 20-45 y, BMI <40kg/m^2^; - [underlined: Age]: 25 (1.1) y; - [underlined: Female]: 49%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: Females: 22.9 (0.6) kg/m^2^; Males: 24.3 (0.4) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting to gain or lose weight, smokers, athlete in training, taking medications that affect appetite, food restrictions or allergies, do not eat meals at regular times, did not like the study food, pregnant or lactating at time of the study, >20 on the Eating Attitudes Test, >40 on the Zung Self-Rating Scale | Intervention:; [underlined: Condition 1]: 6-inch sandwich, 668 kcal; [underlined: Condition 2]: 8-inch sandwich, 892 kcal; [underlined: Condition 3]: 10-inch sandwich, 1,113 kcal; [underlined: Condition 4]: 12-inch sandwich, 1,337 kcal; Duration: 1 meal (lunch) once per week for 4 weeks; Compliance: 100% compliance; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Sandwich intake:; [underlined: Condition 1 (6 inch)]:; Females: 515 (24) kcal; Males: 635 (10) kcal; [underlined: Condition 2 (8 inch)]:; Females: 600 (36) kcal; Males: 804 (22) kcal; [underlined: Condition 3 (10 inch)]:; Females: 619 (35) kcal; Males: 919 (31) kcal; [underlined: Condition 4 (12 inch)]:; Females: 674 (41) kcal; Males: 990 (36) kcal; Females: Condition 1 vs. 2, 3, 4; p<0.05; Condition 2 vs. 1, 4; p<0.05; Condition 3 vs. 1, 4; p<0.05; Condition 4 vs. 1, 2; p<0.05; Males: All conditions, p<0.05 | Model adjustments:; - TEI: NR; - Other: Fixed factor: sandwich size and subject sex; subjects were random effect; Limitations:; - Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; NR
Cunningham, 2023a^37^; RCT-Crossover, U.S.; Baseline N=50, Analytic N=44 (Attrition: 12%); Study objective: To provide novel insights regarding how the common behaviors of switching between foods and beverages and consuming different amounts of water at a meal were related to food intake across meals varying in portion size; Participant characteristics at baseline:; Adults, age 18-70y, BMI between 18-35 kg/m^2^, regularly ate 3 meals/d; - [underlined: Age]: 43.0 (17) y; - [underlined: Female]: 66%; - [underlined: Race and/or ethnicity]: White: 77%; Black: 2%; Asian: 14%; Multiple races: 7%; Hispanic: 5%; - [underlined: Socioeconomic position]: University degree: 66%; HHI >$50k: 52%; Low food security: 7%; - [underlined: Anthropometry]: BMI: ~25 kg/m^2^; Overweight or obesity: 46%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting, smokers, food allergies or restrictions, medications that affect appetite, athletes, pregnant or breastfeeding, disliked study foods, ever diagnosed with depression or an eating disorder, specialized in psychology or nutrition, not willing to refrain from drinking alcohol the day before study meals, willing to eat study food | Intervention:; [underlined: Condition 1]: 100% portion size (400 g, 580 kcal); [underlined: Condition 2]: 125% portion size (500 g, 725 kcal); [underlined: Condition 3]: 150% portion size (600 g, 870 kcal); [underlined: Condition 4]: 175% portion size (700 g, 1015 kcal); Entrée portion size was manipulated (pasta dish); served with water; Duration: 1 meal (lunch) once a week for 4 weeks; Compliance: Three excluding for not liking the test food, 1 withdrew for personal reasons, 1 excluded for failure to follow meal protocols, 1 excluded for undue influence on results; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Entrée intake (kcal):; [underlined: Condition 1 (100% PS)]: 419 (26) kcal; [underlined: Condition 2 (125% PS)]: 506 (26) kcal; [underlined: Condition 3 (150% PS)]: 560 (26) kcal; [underlined: Condition 4 (175% PS)]: 612 (26) kcal; P<0.0001 | Model adjustments:; - TEI: NR; - Other: Fixed factors: portion size, study week, participant sex; Limitations:; - None identified; Funding:; Jenny Craig, Inc
Cahayadi, 2019^38^; RCT-Crossover, New Zealand; Baseline N=86, Analytic N=62 (Attrition: 28%); Study objective: To examine the effects of portion sizes on expected intake during premeal planning and actual consumption, using a within-subject design; Participant characteristics at baseline:; Adults, 18-60 y, healthy; - [underlined: Age]: 23.7 (7.5) y; - [underlined: Female]: 47%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 23.4 (3.0) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting, food allergies or restrictions, consumed pasta at least once a month, untrustworthy questionnaire completion | Intervention:; [underlined: Condition 1]: 100% (400 g); [underlined: Condition 2]: 150% (600 g); [underlined: Condition 3]: 200% (800 g); Duration: 1 meal (lunch); Compliance: Thirteen did not complete the study, 11 excluded due to untrustworthy questionnaires; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Energy intake (kcal):; Portion size had significant main on effect energy intake, P<0.001 (Data not reported; figure only) | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; Differences in attrition not accounted for in analyses; No power calculation; No preregistered data analysis plan; Funding: NR
Zuraikat, 2016^39^; RCT-Crossover, U.S.; Baseline N=50, Analytic N=50 (Attrition: 0%); Study objective: To test whether having subjects choose a portion from several options influenced the amount selected or consumed when all portion sizes were systematically increased; Participant characteristics at baseline:; Adults, age 18-45 y, regularly eat 3 meals; - [underlined: Age]: ~27 y (17.9-45.8 y); - [underlined: Female]: 48%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: ~25 kg/m^2^; Overweight or obesity: 50%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting, food allergies or restrictions, smokers, medications that affect appetite, athletes, scored high on depression scale, scored high for disordered eating, if BMI <18 or >35 kg/m^2^ | Intervention:; Subjects were offered 3 portions of macaroni and cheese, selected a portion, and consumed ad libitum:; Women:; [underlined: Condition 1]: Offered 300 g, 375 g, 450 g; [underlined: Condition 2]: Offered 375 g, 450 g, 525 g; [underlined: Condition 3]: Offered 450 g, 525 g, 600 g; Men:; [underlined: Condition 1]: Offered 400 g, 500 g, 600 g; [underlined: Condition 2]: Offered 500 g, 600 g, 700 g; [underlined: Condition 3]: Offered 600 g, 700 g, 800 g; Duration: 1 meal (lunch) once a week for 3 weeks; Compliance: N/A; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Energy intake (kcal):; Energy intake from the entree chosen from the middle set of portions (condition 2) did not differ significantly from the small set of portions (condition 1), P>0.05; Energy intake from the entree chosen from largest set of portions (condition 3) was significantly greater than from the other two sets (conditions 1, 2) (P < 0.0001) (Energy intake was 16% greater in condition 3 (661 (34) kcal) compared to conditions 1 and 2 (568 (18) kcal) | Model adjustments:; - TEI: NR; - Other: Fixed factors in model: set of portions offered, subject sex, study week; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; NIH
Almiron-Roig, 2015^40^; RCT-Crossover, U.K.; Baseline N=40, Analytic N=37 (Attrition: 8%); Study objective: To test whether increasing the portion size of a meal would lead to an increase in bite size. Secondary objectives were to explore changes in overall eating rate, deceleration rate and meal duration; Participant characteristics at baseline:; Adult women, age 18-60 y, BMI 25-35 kg/m^2^; - [underlined: Age]: 43.7 (10.7) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 29.2 (2.6) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Men, smokers, dieting, in athletic training, breakfast less than 5 days per week, pregnant or lactating, using medications/or having a medical condition known to affect food intake or appetite, not liking study foods, self-reported depression, mental illness, or psychiatric disorder, score high on EAT-26, excessive alcohol intake | Intervention:; [underlined: Condition 1]: 57%, 229 g, 311 kcal; [underlined: Condition 2]: 75%, 303 g, 406 kcal; [underlined: Condition 3]: 100%, 400 g, 526 kcal; [underlined: Condition 4]: 132%, 529 g, 693 kcal; [underlined: Condition 5]: 175%, 700 g, 908 kcal; Duration: 1 meal (lunch) for 5 sessions; Compliance: Three excluded due to scheduling conflicts; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Energy intake (kcal):; [underlined: Condition 1 (57%)]: 301 (2) kcal; [underlined: Condition 2 (75%)]: 394 (15) kcal; [underlined: Condition 3 (100%)]: 518 (37) kcal; [underlined: Condition 4 (132%)]: 688 (17) kcal; [underlined: Condition 5 (175%)]: 889 (89) kcal; P value not reported | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; Medical Research Council
Rolls, 2002^41^; RCT-Crossover, U.S.; Baseline N=59, Analytic N=51 (Attrition: 14%); Study objective: To examine the effect of portion size on intake during a single meal; Participant characteristics at baseline:; Adults, 21-40 y, BMI of 20-28 kg/m^2^; - [underlined: Age]: ~22 (0.5) y; - [underlined: Female]: 49%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: ~23.5 (0.4) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Following a weight-loss diet or trying to gain weight, using medication known to affect food intake or appetite, athletes in training, pregnant or lactating, food allergies or food restrictions that would affect food intake, and not regularly eating 3 meals per day, high scores on dietary restraint, hunger, disinhibition, or depression questionnaires, BMI <20 or >28kg/m^2^ | Intervention:; [underlined: Group 1]: Received all 4 conditions on a plate; [underlined: Group 2]: Received all 4 conditions in a serving dish, and served themselves; [underlined: Condition 1]: 100%, 500 g, 815 kcal; [underlined: Condition 2]: 125%, 625 g, 1019 kcal; [underlined: Condition 3]: 150%, 750 g, 1223 kcal; [underlined: Condition 4]: 200%, 1000 g, 1630 kcal; Entrée portion size was manipulated; subjects were served compulsory carrots and chocolate; Duration: 1 meal (lunch) once a week for 4 weeks; Compliance: Five excluded for not liking the entrée, 2 excluded for scheduling conflicts, 1 excluded due to illness; Outcomes and assessment methods: Weighed food intake; Before and after test meal | [underlined: Condition 1 (100%)]: 546 (25) kcal; [underlined: Condition 2 (125%)]: 610 (31) kcal; [underlined: Condition 3 (150%)]: 652 (36) kcal; [underlined: Condition 4 (200%)]: 707 (42) kcal; P<0.0001; There was not significant effect of serving methods, P=NS | Model adjustments:; - TEI: NR; - Other: Fixed factor effects in the model were portion size (500, 625, 750, and 1000 g) and serving method (plate or serving dish); subjects were treated as a random effect; Limitations:; - Methods for randomization and concealment NR; Did not account for missing data; No power calculation; No preregistered data analysis plan; Funding:; NIH
Rosenthal, 2017^42^; RCT-Crossover, U.S.; Baseline N=20, Analytic N=20 (Attrition: 0%); Study objective: To investigate the independent and interactive effects of television watching and portion size on consumption during a meal; Participant characteristics at baseline:; Adults, 18-35y, BMI 18.5-24.9 kg/m^2^; - [underlined: Age]: 22.3 (3.7) y; - [underlined: Female]: 85%; - [underlined: Race and/or ethnicity]: White: 80%; Hispanic or Latino: 20%; - [underlined: Socioeconomic position]: Education, some college or higher: 100%; Married: 15%; - [underlined: Anthropometry]: BMI: 21.6 (2.3) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: All regularly eat before 10am; Excluded from study or analysis: Restrained eaters, dislike for study foods, did not regularly eat before 10:00 a.m. on most days, unable to complete all sessions within 8 weeks, smokers, taking medications that affected appetite or food intake, pregnant or breastfeeding, on a dietary plan or had dietary restrictions that prevent consumption of certain types and/or amounts of food, self-reported binge eating, athlete in training | Intervention:; [underlined: Condition 1]: 100% portion size, 1083 kcal, TV; [underlined: Condition 2]: 200% portion size, 2166 kcal, TV; [underlined: Condition 3]: 100% portion size, 1083 kcal, No TV; [underlined: Condition 4]: 200% portion size, 2166 kcal, No TV; Duration: 1 meal (lunch) once a week for 4 weeks; Compliance: N/A; Outcomes and assessment methods: Weighed food intake; Before and after test | Total energy intake:; [underlined: 100% portion size]: 734.6 (187.1) kcal; [underlined: 200% portion size]: 903.9 (270.4) kcal; P<0.0001; Main effect of TV watching: P=NS | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization concealment NR; Funding:; NR
Roe, 2016^43^; RCT-Crossover, U.S.; Baseline N=51, Analytic N=48 (Attrition: 6%); Study objective: To investigate the influence of food energy density on the portion size effect as well as that of palatability and subject characteristics; Participant characteristics at baseline:; Adults, women, 20-45y, BMI 18-40 kg/m^2^; - [underlined: Age]: 28.6 (1.2) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 24.4 (0.7) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: All regularly eat 3 meals/day; Excluded from study or analysis: Unwilling to consume study foods, did not regularly eat three meals per day, dieting to gain or lose weight, had food allergies or restrictions, were taking medications known to affect appetite, were smokers or athletes in training, pregnant or breastfeeding, symptoms of depression or disordered eating | Intervention:; [underlined: Condition 1]: 100% portions, 660g, 1056 kcal; [underlined: Condition 2]: 133% portions, 880g, 1408 kcal; [underlined: Condition 3]: 167% portions, 1100g, 1760 kcal; [underlined: Condition 4]: 200% portions, 1320g, 2112 kcal; Duration: 1 meal (lunch) once a week for 4 weeks; Compliance: Two participants failed to attend scheduled meals and did not complete study, 1 participant excluded for not following protocol.; Outcomes and assessment methods: Weighed food intake; Before and after test | Energy intake at lunch:; Increasing the portion size of all foods significantly increased energy intake at the lunch meal; A 33% increase in portion size led to a 24% increase in energy intake; A 67% or 100% increase in portion size led to a 34% increase in energy intake (215 (28) kcal); P<0.0001; Energy intake by food:; Doubling the portions of the medium-ED foods (pasta, cake, garlic bread) increased their intake by 182 (27) kcal; Doubling the portions of the low-ED foods (tomatoes, broccoli, grapes) increased their intake by 33 (6) kcal; P<0.0001 | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; Funding:; NIH
Levitsky, 2004^44^; RCT-Crossover, U.S.; Baseline N=13, Analytic N=13 (Attrition: 0%); Study objective: To examine the effect of the amount of food served on the amount consumed by young adults; Participant characteristics at baseline:; Adults, undergraduate students; - [underlined: Age]: 23 (8.6) y; - [underlined: Female]: 31%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 23.3 (2.9) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Allergic to study food or restraint score >30 | Intervention:; [underlined: Condition 1]: 100% portion sizes; [underlined: Condition 2]: 125% portion sizes; [underlined: Condition 3]: 150% portion sizes; Duration: 1 meal (lunch) 3 days per week for 3 weeks; Compliance: 100% compliance; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Energy Intake, kcal; [underlined: Condition 1]: 698 kcal; [underlined: Condition 2]: 863 kcal; [underlined: Condition 3]: 971 kcal; P<0.05 for all; Increasing the PS for all meal components; increased amount of each component consumed (P<0.01) | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; NR
Zuraikat, 2018a^45^; RCT-Crossover, U.S.; Baseline N=58, Analytic N=53 (Attrition: 9%); Study objective: To test how the effect of portion size on meal intake was influenced by providing the option to take away uneaten food in a “doggy bag” (to-go container); Participant characteristics at baseline:; Adults, women, 18-60y, BMI 18.5-36 kg/m^2^; - [underlined: Age]: 29 (12) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: White: 82%; Black: 4%; Asian: 14%; Hispanic or Latino: 8%; - [underlined: Socioeconomic position]: NR; HHI >$50k: 54%; - [underlined: Anthropometry]: BMI: 25 (4) kg/m^2^ Overweight or obesity: 36%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: All regularly consume 3 meals/day; Excluded from study or analysis: Did not regularly ate 3 meals per day, unwilling to eat the foods served at the meal, unwilling to refrain from drinking alcohol the day before their scheduled experimental sessions, smokers, athletes in training, dieting to gain or lose weight, taking medications known to affect appetite, pregnant or breastfeeding, allergies or intolerances to the foods served, medical condition known to affect eating, signs of disordered eating as indicated by Eating Attitudes Test score | Intervention:; Group 1: Control group (no option to take leftovers to-go); [underlined: Condition 1]: 100%, 560 g, 828 kcal; [underlined: Condition 2]: 125%, 700 g, 1035 kcal; [underlined: Condition 3]: 150%, 840 g, 1243 kcal; [underlined: Condition 4]: 175%, 980 g, 1449 kcal; Group 2: Doggy bag group (provided with a doggy bag to take leftovers to-go); [underlined: Condition 1]: 100%, 560 g, 828 kcal; [underlined: Condition 2]: 125%, 700 g, 1035 kcal; [underlined: Condition 3]: 150%, 840 g, 1243 kcal; [underlined: Condition 4]: 175%, 980 g, 1449 kcal; Duration: 1 meal (dinner) once a week for 4 weeks; Compliance: Four excluded for withdrawing, and 1 excluded for failing to comply with study protocols; Outcomes and assessment methods: Weighed food intake; Before and after test meal | Total energy intake at lunch:; Group 1: Control group (no option to take leftovers to-go); [underlined: Condition 1 (100%)]: 602.8 (26.6) kcal; [underlined: Condition 2 (125%)]: 679 (31.9) kcal; [underlined: Condition 3 (150%)]: 776.4 (37.1) kcal; [underlined: Condition 4 (175%)]: 759.4 (48.3) kcal; Group 2: Doggy bag group (provided with a doggy bag to take leftovers to-go); [underlined: Condition 1 (100%)]: 599.4 (26.5) kcal; [underlined: Condition 2 (125%)]: 606.7 (26.8) kcal; [underlined: Condition 3 (150%)]: 671 (28.9) kcal; [underlined: Condition 4 (175%)]: 686 (34.2) kcal; Portion size effect: P<0.0001; Group effect: P<0.025; Individual foods (grams), PS effect, Group effect:; [underlined: Chicken]: P=0.07, P<0.04; [underlined: Pasta]: P=0.31, P<0.03; [underlined: Broccoli]: P<0.0001, P=0.22; [underlined: Garlic bread]: P=0.0005, P=0.38; [underlined: Grapes]: P=0.005, P=0.91 | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization concealment not reported; No preregistered data analysis plan; Funding:; NIH, USDA, Jenny Craig, Inc.
Zuraikat, 2018c^46^; RCT-Crossover, U.S.; Baseline N=105, Analytic N=102 (Attrition: 3%); Study objective: To evaluate whether the effect of portion size on intake in a controlled setting was attenuated in trained participants compared to untrained controls; Participant characteristics at baseline:; Adults, women, 20-65 y; - [underlined: Age]: 43.2 (13.6) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: White: 97%; Black: 2%; Asian: 1%; Hispanic or Latino: 4%; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]:; All BMI: 28.0 (3.5) kg/m^2^; Trained participants: 32.3 (4.8) kg/m^2^; Controls with overweight/obesity: 29.5 (4.0) kg/m^2^; Controls with normal weight: 22.3 (1.6) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Trained participants: based on Rolls et al., 2017^75^ Portion Control Strategies Trial; Control: Showed evidence of disordered eating <19 on the Eating Attitudes Test or <40 on the Depression Scale, had food allergies, restrictions, or disliked study foods, did not regularly eat 3 meals per day, were dieting to gain or lose weight, were smokers, athletes in training, pregnant or breastfeeding. | Intervention:; [underlined: Condition 1]: 100%, 594g, 808 kcal; [underlined: Condition 2]: 125%, 743g, 1010 kcal; [underlined: Condition 3]: 150%, 891g, 1212 kcal; [underlined: Condition 4]: 175%, 1040g, 1414 kcal; Duration: 1 meal (lunch) once a week for 4 weeks; Compliance: Three subjects failed to attend all scheduled meals; Outcomes and assessment methods:; Weighed food intake; Before and after test meal | Breaded chicken, kcal, condition 1, 2, 3, 4; [underlined: Trained Participants]: 118.8 (6.7), 124.6 (8.6), 135.2 (9.5), 138.4 (10.4); [underlined: Controls with overweight and obesity]: 124.6 (6.1), 135.4 (8.6), 152 (11.5), 162.8 (12.1); [underlined: Controls with normal weight]: 122 (6.1), 147.7 (8.9), 174.5 (10.8), 150.5 (14.5); Portion size effect: P=0.002; Group effect: P=0.07; Pasta, kcal, condition 1, 2, 3, 4; [underlined: Trained participants]: 113.3 (11.7), 105.4 (14.4), 106.8 (16), 131.7 (16.1); [underlined: Control with overweight and obesity]: 130.8 (12.8), 133.2 (14.9), 133.2 (16.7), 163 (19.5); [underlined: Controls with normal weight]: 134 (14.1), 155.7 (17.1), 161 (21.8), 163.3 (20.8); Portion size effect: P=0.005 Group effect: P<0.0001; intake of trained participants<intake of controls with normal weight; Broccoli, kcal, condition 1, 2, 3, 4; [underlined: Trained Participants]: 32.9 (1.2), 37.7 (1.8), 44.2 (2.3), 44.9 (2.8); [underlined: Control with overweight and obesity]: 31.1 (1.7), 34.9 (2.2), 40.5 (2.7), 42.7 (3.4); [underlined: Controls with normal weight]: 29.6 (1.8), 33.7 (2.8), 39.1 (3), 37.8 (4); Portion size effect: P<0.001; Group effect: P=0.09; Salad, kcal, condition 1, 2, 3, 4; [underlined: Trained participants]: 36.7 (2.1), 45.9 (2.2), 49.1 (3.7), 54 (4); [underlined: Control with overweight and obesity]: 37 (1.8), 43.2 (2.5), 47.3 (3.3), 53.2 (4); [underlined: Control with normal weight]: 31.1 (2.8), 32.8 (3.8), 43 (4.2), 38.7 (5); Portion size effect: P<0.0001; Group effect: P<0.0001; trained participants and controls with overweight and obesity>intake of controls with normal weight; Garlic bread, kcal, condition 1, 2, 3, 4; [underlined: Trained participants]: 73.1 (9.4), 76.7 (11.5), 87.1 (12.6), 113 (14.8); [underlined: Control with overweight and obesity]: 118.1 (9.7), 125.3 (12.2), 153.4 (11.5), 137.2 (14.4); [underlined: Control with normal weight]: 114.8 (10.4), 122.8 (13), 143.3 (16.6), 159.9 (16.2); Portion size effect: P=0.043; Group effect: P=0.004; intake of trained participants<both control groups; Grapes, kcal, condition 1, 2, 3, 4; [underlined: Trained participants]: 42.2 (2.9), 46.5 (3.2), 51.4 (3.8), 46.6 (4.8); [underlined: Control with overweight and obesity]: 38.5 (3.2), 36.3 (4.1), 43 (5.1), 45.9 (5.7); [underlined: Control with normal weight]: 41.4 (3.3), 38; [underlined: Control with normal weight:] 41.4 (3.3), 38 (4.8), 43.5 (5.9), 43.5 (6.3); Portion size effect: P=0.11; Group effect: P=0.12; Cookie, kcal, condition 1, 2, 3, 4; [underlined: Trained participants]: 43.1 (7.7), 37.8 (8.2), 40.7 (9.2), 46 (11.1); [underlined: Control with overweight and obesity]: 44 (8.2), 53.2 (10.2), 55.7 (11.6), 55.2 (11.6); [underlined: Control with normal weight]: 61 (8.7), 55.7 (10.6), 52.3 (11.1), 70.7 (13.1); Portion size effect: P=0.78; Group effect: P=0.69; For all groups, serving larger portion significantly increased energy intake at the meal, P<0.001; Across all meals, kcal; [underlined: Trained participants]: 506 (15) kcal; [underlined: Controls with overweight and obesity]: 592 (16) kcal; [underlined: Controls with normal weight]: 611 (17) kcal P=0.026; [underlined: Trained participants]: No effect of energy intake according to type of portion-control intervention, P=0.39 | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; NIH, USDA
Long, 2023^47^; RCT-Crossover, U.S.; Baseline N=101, Analytic N=91 (Attrition: 10%); Study objective: To test whether manipulating PS in an iVR buffet affects the weight of food selected, and whether this response to PS is similar to participants’ measured intake when PS varies at laboratory meals; Participant characteristics at baseline:; Adults, 18 y or older; - [underlined: Age]: 29 (14) y; - [underlined: Female]: 70%; - [underlined: Race and/or ethnicity]: White: 56%; Asian: 31%; Other: 13%; - [underlined: Socioeconomic position]: Advanced degree: 25%, bachelor’s degree: 24%, Some college: 33%; <20k/y: 55%; - [underlined: Anthropometry]: BMI: 25.3 (5.7) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Not fluent in English, food allergies, not open to eating all food items, prior diagnosis of cognitive or physical disabilities, dyslexia, or epilepsy | Intervention:; [underlined: Condition 1]: Standard portion, 515 g, 747 kcal; [underlined: Condition 2]: Larger portion, 917 g, 1361 kcal; Subjects participated in a virtual reality buffet portion size selection task before being served lunch in the laboratory; All foods served were manipulated (chicken, pasta, cheese, broccoli, grapes, rolls, cookies), but only total intakes were reported; Duration: 1 meal once a week for 2 weeks; Compliance: One was excluded for violating protocol, 3 were excluded for dropping out, 6 were excluded due to equipment errors; Outcomes and assessment methods:; Weighed food intake; Before and after test meal | [underlined: Condition 1]: 547 (13) kcal; [underlined: Condition 2]: 762 (26) kcal; P<0.001 | Model adjustments:; - TEI: NR; Limitations:; - Randomization concealment NR; No pre-registered data analysis plan; Difficult to isolate the effects of portion size served on intake from the virtual reality task; Funding:; The Pennsylvania State University
Jeffery, 2007^48^; RCT-Crossover, U.S.; Baseline N=20, Analytic N=19 (Attrition: 5%); Study objective: To examine the effects of repeated exposure to different meal portion sizes on energy intake; Participant characteristics at baseline: Women, employees of a community medical center, 18-40y, 18.5-40 kg/m^2^; - [underlined: Age]: 33 (5.2) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: White: 80%; - [underlined: Socioeconomic position]: At least 4y college degree: 65%; Married: 45%; - [underlined: Anthropometry]: BMI: 28.9 (7.8) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Pregnant or recently having given birth, actively dieting to control weight, more than 3 days a week of regular moderate or vigorous physical activity, unwillingness to consent to the conditions of study participation | Intervention:; [underlined: Condition 1]: Box lunch 100%: ~767 kcal, Monday-Friday; [underlined: Condition 2]: Box lunch 200%: ~1528 kcal, Monday-Friday; Box lunches were identical, and only portion sizes differed; Duration: 1 meal (lunch) for 8 weeks; Compliance: Completion of post-lunch meal reports was 91%, and of telephone recalls of diet and activity was 98%, 1 participant withdrew early due to a health problem.; Outcomes and assessment methods:; Two 24-hr recalls during each 4-week period; Participants self-reported how much of each lunch was eaten; 4 weeks | Energy intake from lunch (kcal):; [underlined: Condition 1]: 687 kcal; [underlined: Condition 2]: 1019 kcal; P<0.0001; Total daily energy intake (kcal):; [underlined: Condition 1]: 1875 kcal; [underlined: Condition 2]: 2153 kcal; P<0.0001 | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; Concerns with the validity of outcome self-reporting; Did not account for the rest of the diet; No preregistered data analysis plan; Funding:; NIH; University of Minnesota Obesity Prevention Center
Rolls, 2006a^49^; RCT-Crossover, U.S.; Baseline N=32, Analytic N=32 (Attrition: 0%); Study objective: To test the effect on energy intake of increasing the portion size of all foods and beverages served over 2 consecutive days; Participant characteristics at baseline: Adults, 19-45 y; - [underlined: Age]: 22.8 (0.9) y; - [underlined: Female]: 50%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 23.5 (0.6) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting to gain or lose weight, athlete in training, pregnant or breastfeeding, taking medications known to affect appetite, food allergies or dislikes for the entrees and dessert served in study, not regularly consuming 3 meals per day, BMI <19 or >30 kg/m^2^, scored >40 on the Zung Scale, >20 on the Eating Attitudes Test | Intervention:; [underlined: Condition 1]: 100% portion sizes; [underlined: Condition 2]: 150% portion sizes; [underlined: Condition 3]: 200% portion sizes; Duration: All meals and snacks on 2 consecutive days for 3 weeks; Compliance: 100% compliance; Outcomes and assessment methods:; Weighed food intake; Before and after test meals | Energy Intake over 2 days:; Condition 1 vs. 2 and 3: Women and men, P<0.0008; Condition 2 vs. 3: Women, P=NS; Men, P<0.0008; Energy intake per day:; Condition 1 (100%) vs. Condition 2 (150%): +335 kcal/day for women; +504 kcal/day for men; P<0.0001; Condition 1 (100%) vs. Condition 3 (200%): +530 kcal/day for women; +812 kcal/day for men; P<0.0001; Larger portion sizes significantly increased intake from all food categories (entrees, starches, fruit and vegetable side dishes, desserts, condiments, beverages, and snacks): P<0.02 | Model adjustments:; - TEI: NR; - Other: Fixed factors: subject sex, portion size condition; Limitations:; - Methods for randomization and concealment NR; No power calculation; Snacks consumed at home so may limit compliance/adherence; No preregistered data analysis plan; Funding:; NIH
Rolls, 2006b^50^; RCT-Crossover, U.S.; Baseline N=25, Analytic N=24 (Attrition: 4%); Study objective: To test the combined effects of portion size and energy density on energy intake over 2 days; Participant characteristics at baseline:; Adult women, age 19-45y, BMI between 18-40 kg/m^2^, regularly eat 3 meals; - [underlined: Age]: ~22 (1) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: ~23 kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% non-smokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting, food allergies or restrictions, medications that affect appetite, athletes, pregnant or breastfeeding, disliked study foods, scored high on depression scale, scored high for disordered eating, smokers | Intervention:; [underlined: Condition 1]: 75% portion size, 75% ED; [underlined: Condition 2]: 100% portion size, 75% ED; [underlined: Condition 3]: 75% portion size, 100% ED; [underlined: Condition 4]: 100% portion size, 100% ED; Duration: 2 days; Compliance: One participant was excluded for non-compliance; Outcomes and assessment methods:; Weighed food intake; Before and after every test meal | [underlined: Condition 1]: 3355 (114) kcal; [underlined: Condition 2]: 3873 (125) kcal; [underlined: Condition 3]: 4449 (145) kcal; [underlined: Condition 4]: 4955 (143) kcal | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; NIH
Kelly, 2009^51^; RCT-Crossover, Ireland; Baseline N=44, Analytic N=43 (Attrition: 2%); Study objective: To determine the extent to which the availability of different-sized predefined and pre-packed food portions would affect the amounts of food consumed, EI and self-perceived appetite sensations in normal-weight and overweight adults over four consecutive days under fully residential conditions; Participant characteristics at baseline:; Adults, 18-65 y; - [underlined: Age]: 30.7 (7.1) y; - [underlined: Female]: 51%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 24.5 (3.1) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Smokers, vegetarians, those taking prescription medications or any drugs that might interfere with normal food intake, food allergies or dietary restrictions, chronic disease, BMI <18.5 or >30, unwilling to participate in a fully residential study, or did not like the study menu | Intervention:; [underlined: Condition 1]: Standard portions; [underlined: Condition 2]: Large portions; Duration: 2, 4-day periods; Compliance: One was excluded for not complying with the study protocol; Outcomes and assessment methods:; Weighed food intake; Before and after each test meal | Energy Intake, kcal per day:; [underlined: Men, large vs. standard portions]:; +573.6 (382.4) kcal; P=0.001; [underlined: Women, large vs standard portions]:; + 262.9 (382.4) kcal; P=0.005; Meal Intake:; [underlined: Men and Women]:; Larger portion>Standard; P=0.001; Energy intake, cumulative over 4 days; [underlined: Men, large vs. standard portions]:; 16,300.2 (4,182.6) kcal vs. 14,005.7 (3,776.3) kcal; P=0.001; [underlined: Women, large vs. standard portions]:; 12,022 (2,366.2) kcal vs. 9,560.2 (2,294.5) kcal; P=0.005 | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; Food Standards Agency
Rolls, 2007^52^; RCT-Crossover, U.S.; Baseline N=27, Analytic N=23 (Attrition: 15%); Study objective: To determine whether participants would compensate for excess energy intake or continue to overeat when; portion sizes were increased for 11 days; Participant characteristics at baseline:; Adults, 20-40 y, BMI 18.5-30 kg/m^2^; - [underlined: Age]: 25.3 (1.9) y; - [underlined: Female]: 43%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 23.8 (0.8) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Smokers, BMI <18 or >30; did not regularly eat 3 meals per day, were dieting to gain or lose weight, athletes in training, taking medications known to affect appetite, pregnant or breastfeeding, food allergies or restrictions, did not like or unwilling to eat study foods, not willing to refrain from drinking alcohol during study period, scored >40 on the Zung Self-Rating Scale, and >20 on Eating Attitudes Test | Intervention:; [underlined: Condition 1]: 100% portions; [underlined: Condition 2]: 150% portions; Duration: All meals and snacks for 2, 11-day periods; Compliance: Three participants excluded for failing to comply with the study schedule or protocol; 1 excluded for consuming substantially less than estimated daily energy requirements on multiple days; Outcomes and assessment methods:; Weighed food intake; Before and after meals | Total Energy Intake (kcal/d); [underlined: Women]: 1 vs 2: 2073 (97), 2530 (70); [underlined: Men]: 1 vs 2: 2909 (106), 3328 (114); P<0.0001; Cumulative Energy Intake; P<0.0001; Food Energy (kcal/d); Condition 1, 100%, Condition 2, 150%; [underlined: Total food energy]:; Women: 1891 (81), 2308 (66); Men: 2709 (97), 3063 (101); P<0.0001; [underlined: Entree]:; Women: 941 (51), 1077 (56);; Men: 1432 (47), 1593 (72); P=0.003; [underlined: Starches]:; Women: 196 (12), 250 (19); Men: 299 (12), 339 (15); P<0.0001; [underlined: Vegetables]:; Women: 65 (11), 72 (14); Men: 75 (11), 69 (8) NS; [underlined: Desserts and yogurts]:; Women: 327 (16), 407 (22); Men: 471 (24), 556 (27); P<0.0001; [underlined: Fruit with a meal]:; Women: 47 (4), 52 (7); Men: 71 (4), 88 (6); P=0.0016; [underlined: Fruit as a snack]:; Women: 30 (5), 37 (7); Men: 38 (6), 40 (7); NS; [underlined: Snack foods]:; Women: 285 (21), 413 (28); Men: 322 (38), 377 (43); P<0.0001; Beverage energy, kcal/d; Women: 183 (25), 221 (33); Men: 199 (19), 265 (25); P<0.0001 | Model adjustments:; - TEI: NR; - Other: Fixed factors: portion size condition, menu number, and participant sex; Limitations:; - Methods for randomization and concealment NR; Not sufficiently powered; compliance/adherence on non-laboratory meals (weekend/snacks); No preregistered data analysis plan; Funding:; NIH
Levitsky, 2020^53^; RCT-Crossover, U.S.; Baseline N=81, Analytic N=74 (Attrition: 9%); Study objective: To examine the effect of decreasing portion size of an entrée on the amount of dessert subsequently consumed; Participant characteristics at baseline:; College students in an introductory nutrition course, >18 y; - [underlined: Age]: 19.6 (5.9) y; - [underlined: Female]: 84%; - [underlined: Race and/or ethnicity]: White: 50%; Nonwhite: 50%; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 21.6 (3.1) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Food allergies or restrictions, missing data | Intervention:; [underlined: Control]: Ad libitum consumption of entrée and dessert; [underlined: Condition 1]: 100% of entree + dessert; [underlined: Condition 2]: 90% of entree + dessert; [underlined: Condition 3]: 85% of entree + dessert; [underlined: Condition 4]: 80% of entree + dessert; Dessert was not manipulated; Subjects were served an entree portion based on 100% of what they consumed at the control session; Duration: 1 meal (lunch) once a week for 5 weeks; Compliance: Seven excluded for not completing all conditions; 23 with missing dessert values that were square root transformed; Outcomes and assessment methods:; Weighed food intake; Before and after test meal | Entree energy intake, kcal:; [underlined: Control, Condition 1]: 359 kcal; [underlined: Condition 2]: NR; [underlined: Condition 3]: NR; [underlined: Condition 4]: 252.7 kcal; P not reported; Dessert energy intake, kcal:; All conditions: 94.8 kcal; P=NS across conditions | Model adjustments:; - TEI: NR; - Other: fixed factor effects in the model were portion size condition, height, weight, gender, age, and leftovers; subjects were treated as a random effect; Limitations:; - High loss to follow-up and missing outcome data; subjects were aware of study purpose; did not report data or results clearly for all conditions; no pre-registered data analysis plan; Funding: NR
Rolls, 2004c^54^; RCT-Crossover, U.S.; Baseline N=50, Analytic N=42 (Attrition: 16%); Study objective: To test the effect on meal intake of varying the energy density and portion size of a compulsory first course salad; Participant characteristics at baseline:; Women, age 19-45 y, BMI between 18-40 kg/m^2^, regularly eat 3 meals; - [underlined: Age]: 26.3 (1.2) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 23.7 (0.6) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting, food allergies or restrictions, smokers, medications that affect appetite, athletes, pregnant or breastfeeding, disliked study foods, scored high on depression scale, scored high for disordered eating | Intervention:; [underlined: Condition 1]: 100% portion size, low energy density (0.33 kcal/g) preload salad; [underlined: Condition 2]: 100% portion size, medium energy density (0.67 kcal/g) preload salad; [underlined: Condition 3]: 100% portion size, high energy density (1.33 kcal/g) preload salad; [underlined: Condition 4]: 200% portion size, low energy density (0.33 kcal/g) preload salad; [underlined: Condition 5]: 200% portion size, medium energy density (0.67 kcal/g) preload salad; [underlined: Condition 6]: 200% portion size, high energy density (1.33 kcal/g) preload salad; [underlined: Condition 7]: No preload salad; Subjects were required to consume the entire salad preload, and then consumed an entree(pasta) ad libitum; Duration: 1 meal (lunch) once a week for 7 weeks; Compliance: Three dropped out due to scheduling, 5 were excluded because the consumed the entire entrée; Outcomes and assessment methods:; Weighed food intake; Before and after test meal | Entree intake:; PS Conditions 4, 5, 6 vs. 1, 2,3: −98 (30) kcal; P<0.001; ED Conditions 3, 6 vs. 2, 5 and 1, 4; P=0.06; Total meal intake:; Condition 1 vs. 7: −64 (26) kcal; P<0.05; Condition 2 vs. 7; NS; Condition 3 vs. 7: +71 (27) kcal; P<0.05; Condition 4 vs. 7: −107 (29) kcal; P<0.001; Condition 5 vs. 7; NS; Condition 6 vs. 7: +145 (22) kcal; P<0.001; ED alone: P<0.001; Condition 3 vs. Condition 6: +74 (24) kcal; P=0.002; Condition 2 vs Condition 4: −55 (24) kcal; P=0.02; Condition 3 vs Condition 5: −97 (25) kcal; P<0.0001 | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; Excluded data for subjects who consumed the entire entrée, so unclear how that would have affected results; No preregistered data analysis plan; Funding:; NIH
Williams, 2014^55^; RCT-Crossover, U.S.; Baseline N=53, Analytic N=46 (Attrition: 13%); Study objective: To test the effects of varying the energy density and portion size of food consumed after a preload on energy intake; Participant characteristics at baseline:; Women, age 20-45 y, BMI between 18-40 kg/m^2^, regularly eat 3 meals; - [underlined: Age]: 25.4 (0.8) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 23.6 (0.5) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% non-smokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting, food allergies or restrictions, medications that affect appetite, athletes, pregnant or breastfeeding, disliked study foods, scored high on depression scale, scored high for disordered eating, did not regularly eat 3 meals per day, smoked | Intervention:; [underlined: Condition 1]: 100% energy density 1.25 kcal/g), 100% portion size (450g, 563 kcal); [underlined: Condition 2]: 100% energy density 1.25 kcal/g), 133% portion size (600g, 750 kcal); [underlined: Condition 3]: No salad preload, 100% energy density 1.25 kcal/g), 133% portion size (600g, 750 kcal); [underlined: Condition 4]: 133% energy density 1.66 kcal/g), 100% portion size (450g, 747 kcal); [underlined: Condition 5]: 133% energy density 1.66 kcal/g), 133% portion size (600g, 750kcal); [underlined: Condition 6]: No salad preload, 133% energy density 1.66 kcal/g), 133% portion size (600g, 750 kcal); Subjects were served a compulsory salad preload (300g, 100 kcal), followed by an ad libitum pasta dish (ED was manipulated by changing proportions of pasta cheese, cream, sauce, and pureed vegetables).; Standard breakfast was served to participants:bagel and yogurt; Duration: 1 meal (lunch) once a week for 6 weeks; Compliance: Three participants were excluded for not following procedures, 3 were excluded for eating the entire test meal on 2 or more occasions; 1 was excluded for highly variable intakes; Outcomes and assessment methods:; Weighed food intake; Before and after test meal | Total pasta intake (kcal), total lunch intake (kcal):; [underlined: Condition 1]: 329 (18), 429 (18); [underlined: Condition 2]: 351 (20), 451 (20); [underlined: Condition 3]: 476 (16), 476 (16); [underlined: Condition 4]: 457 (20), 557 (20); [underlined: Condition 5]: 523 (22), 623 (23); [underlined: Condition 6]: 649 (23), 649 (23); Energy density: P<0.0001, P<0.0001; Portion size: P<0.02, P<0.02; Preload: P<0.0001; NS | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; NIH
Shimpo, 2018^56^; RCT-Crossover, Japan; Baseline N=NR, Analytic N=21 (Attrition: NR); Study objective: To investigate the effects of portion size and bowl size and possible interactions between these variables on food intake and fullness; Participant characteristics at baseline:; Adult men, age 20-60 y; - [underlined: Age]: 39.9 (9.8) y; - [underlined: Female]: 0%; - [underlined: Race and/or ethnicity]: Likely majority Japanese; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 23.6 (2.4) kg/m^2^; - [underlined: Physical activity]: 29% low, 67% moderate, 5% high; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Food allergies to the meals provided | Intervention:; [underlined: Condition 1]: 100%, 150 g in small bowl + lunch; [underlined: Condition 2]: 100%, 150 g in large bowl + lunch; [underlined: Condition 3]: 166%, 250 g in small bowl + lunch; [underlined: Condition 4]: 166%, 250 g in large bowl + lunch; The same lunch was served in all conditions (445 kcal): fried chicken, tomato salad, coleslaw, green tea; Subjects were permitted to obtain refills; Duration: 1 meal (lunch) once a week for 4 weeks; Compliance: NR; Outcomes and assessment methods:; Weighed food intake; Before and after test meal | Intake of rice (g):; [underlined: Condition 1]: 166.7 (45) g; [underlined: Condition 2]: 161.9 (37.6) g; [underlined: Condition 3]: 245.5 (20.7) g; [underlined: Condition 4]: 245.2 (22) g; Portion size: P<0.001; Bowl size: P=NS; Energy intake from the meal (kcal):; [underlined: Condition 1]: 725 kcal; [underlined: Condition 2]: 717 kcal; [underlined: Condition 3]: 857 kcal; [underlined: Condition 4]: 857 kcal; Portion size: P<0.001; Bowl size: P=NS | Model adjustments:; - TEI: NR; Limitations:; - Randomization concealment NR; Did not describe or account for those lost to follow-up; No pre-registered data analysis plan; Funding:; JSPS KAKENHI
Rolls, 2004a^57^; RCT-Crossover, U.S.; Baseline N=68, Analytic N=60 (Attrition: 12%); Study objective: To determine how the portion size of a packaged snack affects energy intake of the snack and of the subsequent meal; Participant characteristics at baseline:; Adults, age 20-45 y, BMI between 20-40 kg/m^2^; - [underlined: Age]: ~23 (1) y; - [underlined: Female]: 57%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: ~23 (1) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Dieting, food allergies or restrictions, medications that affect appetite, athletes, pregnant or breastfeeding, disliked study foods, scored high on depression scale, scored high for disordered eating, did not regularly snack between meals, smokers | Intervention:; [underlined: Condition 1]: 100%, 28 g, 151 kcal; [underlined: Condition 2]: 150%, 42 g, 227 kcal; [underlined: Condition 3]: 300%, 85 g, 459 kcal; [underlined: Condition 4]: 457%, 128 g, 691 kcal; [underlined: Condition 5]: 600%, 170 g, 918 kcal; The same dinner was served ~3hrs later (pasta, salad, bread, chocolate bars, chocolate cookies, water); Duration: 2 meals (snack, dinner) for 5 sessions; Compliance: Five excluded for personal or schedule reasons, 3 excluded for repeated low snack intakes; Outcomes and assessment methods:; Weighed food intake; Before and after test meal | WOMEN:; Energy intake, snack (kcal):; [underlined: Condition 1 (100%)]: 136 (5) kcal; [underlined: Condition 2 (150%)]: 185 (9) kcal; [underlined: Condition 3 (300%)]: 271 (19) kcal; [underlined: Condition 4 (457%)]: 295 (22) kcal; [underlined: Condition 5 (600%)]: 319 (26) kcal; P<0.05 for 1 vs 2, 3, 4, 5; 2 vs 3, 4, 5;; P=NS for 3 vs 4, 5; 4 vs 5; Energy intake, dinner (kcal):; [underlined: Condition 1 (100%)]: 928 (47) kcal; [underlined: Condition 2 (150%)]: 914 (41) kcal; [underlined: Condition 3 (300%)]: 873 (44) kcal; [underlined: Condition 4 (457%)]: 833 (30) kcal; [underlined: Condition 5 (600%)]: 886 (35) kcal; P=NS for all comparisons; Energy intake, snack + dinner (kcal):; [underlined: Condition 1 (100%)]: 1063 (49) kcal; [underlined: Condition 2 (150%)]: 1099 (46) kcal; [underlined: Condition 3 (300%)]: 1145 (53) kcal; [underlined: Condition 4 (457%)]: 1129 (41) kcal; [underlined: Condition 5 (600%)]: 1206 (43) kcal; P<0.05 for 1 vs 5, all other comparisons; P=NS; MEN:; Energy intake, snack (kcal):; [underlined: Condition 1 (100%)]: 142 (4) kcal; [underlined: Condition 2 (150%)]: 212 (7) kcal; [underlined: Condition 3 (300%)]: 330 (27) kcal; [underlined: Condition 4 (457%)]: 443 (31) kcal; [underlined: Condition 5 (600%)]: 452 (45) kcal; P<0.05 for 1 vs 2, 3, 4, 5; 2 vs 3, 4, 5; 3 vs 4, 5; P=NS for 4 vs. 5; Energy intake, dinner (kcal):; [underlined: Condition 1 (100%)]: 1241 (63) kcal; [underlined: Condition 2 (150%)]: 1179 (69) kcal; [underlined: Condition 3 (300%)]: 1167 (47) kcal; [underlined: Condition 4 (457%)]: 1229 (66) kcal; [underlined: Condition 5 (600%)]: 1079 (46) kcal; P<0.05 for 1, 2, 4 vs 5, all other comparisons P=NS; Energy intake, snack + dinner (kcal):; [underlined: Condition 1 (100%)]: 1383 (63) kcal; [underlined: Condition 2 (150%)]: 1390 (71) kcal; [underlined: Condition 3 (300%)]: 1497 (59) kcal; [underlined: Condition 4 (457%)]: 1671 (85) kcal; [underlined: Condition 5 (600%)]: 1531 (73) kcal; P<05 for 1 vs 3, 4, 5; 2 vs 4, 5; 3 vs 4; 4 vs 5 | Model adjustments:; - TEI: NR; - Other: Fixed factors in model: snack package size, subject sex; Limitations:; - Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; NIH
Flood, 2006^58^; RCT-Crossover, U.S.; Baseline N=40, Analytic N=33 (Attrition: 18%); Study objective: To test the effects of increasing beverage portion size on beverage intake, as well as on food and energy intake, during a meal; Participant characteristics at baseline:; Adults, 18-45 y; - [underlined: Age]: 22.5 (0.3) y; - [underlined: Female]: 55%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 23.6 (0.3) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Taking medications that are known to affect appetite or food intake, smokers, do not regularly consume 3 meals a day, dieting to gain or lose weight, athletes in training, pregnant or breastfeeding, food allergies and food restrictions, don’t like soda, score high on the dietary restraint, hunger, disinhibition, or depression questionnaires | Intervention:; [underlined: Condition 1]: 100% (360 g, 0 kcal) water + lunch; [underlined: Condition 2]: 150% (540 g, 0 kcal) water + lunch; [underlined: Condition 3]: 100% (360 g, 0 kcal) diet cola + lunch; [underlined: Condition 4]: 150% (540 g, 0 kcal) diet cola + lunch; [underlined: Condition 5]: 100% (360 g, 150 kcal) cola + lunch; [underlined: Condition 6]: 150% (540 g, 225 kcal) cola + lunch; Lunch consisted of pasta with tomato sauce, salad, a roll, and chocolate chip cookies; Duration: 1 meal (lunch) once a week for 6 weeks; Compliance: Four excluded for consuming the entire lunch meal, 3 excluded for not following protocol or missing meals; Outcomes and assessment methods:; Weighed food intake; Before and after test meal | Beverage intake (kcal):; [underlined: Condition 5 (100% cola)]: 128 (4) kcal; [underlined: Condition 6 (150% cola)]: 151 (8) kcal; P<0.004; Food intake (kcal):; Food intake at lunch did not differ significantly by condition (for portion size or type of beverage), P=NS; Total meal intake (kcal):; Total energy intake at lunch was significantly greater for conditions 5, 6 (cola) vs conditions 1, 2, 3, 4 (water or diet cola), P<0.001 | Model adjustments:; - TEI: NR; - Other: fixed factor effects in the model were beverage type, beverage portion size, and subject sex; awareness of the purposes of the study was also tested as an independent factor in the model; Limitations:; - Randomization concealment NR; Did not account for those lost to follow-up; No pre-registered data analysis plan; Funding:; NIH
Zuraikat, 2018b^59^; RCT-Crossover, U.S.; Baseline N=82, Analytic N=79 (Attrition: 4%); Study objective: To test whether the amount of money paid for a meal influenced the portion size effect at a lunch served in a controlled restaurant-style setting; Participant characteristics at baseline:; Adults, 20-65 y; - [underlined: Age]: 33.9 (12.7) y; - [underlined: Female]: 70%; - [underlined: Race and/or ethnicity]: White: 79%; Black or African American: 6%; Asian: 9%; Mixed or unreported race: 5%; Hispanic or Latino: 6%; - [underlined: Socioeconomic position]: HHI >$50,000: 61%; - [underlined: Anthropometry]: BMI: 25.6 (5.0) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: 2205 (392); - [underlined: Habitual diet at baseline]: All regularly consume 3 meals/day; Excluded from study or analysis: Were not willing to refrain from eating between 10pm the evening before a test day and breakfast on the day of the test and to refrain from consuming alcohol the day before the test session, don’t regularly eat 3 meals per day, they disliked or were unable to eat test foods (allergies, intolerances, dietary restrictions), smokers, taking medication that affected appetite, were diagnosed with a health condition that affects appetite, were dieting to gain or lose weight, athlete in training, pregnant or breastfeeding. | Intervention:; [underlined: Condition 1]: 100% (400g, 636 kcal), $8; [underlined: Condition 2]: 100% (400g, 636 kcal), $16; [underlined: Condition 3]: 150% (600g, 954 kcal), $8; [underlined: Condition 4]: 150% (600g, 954 kcal), $16; Duration: 1 meal (lunch) once a week for 4 weeks; Compliance: Three subjects withdrew due to scheduling conflicts; Outcomes and assessment methods:; Weighed food intake; Before and after test | Lunch intake (kcal); Condition 1, 2 vs. Condition 3, 4: +133 (16) kcal, P<0.0001; Pasta Intake (kcal); Condition 1, 2 vs. Condition 3, 4: +140 (15) kcal; P<0.0001; Bread roll intake (kcal); Condition 1, 2 vs. Condition 3, 4: −4.2 (2) kcal; P<0.019; Salad with dressing intake: NS; Cost of meal did not affect response to PS of the pasta dish. | Model adjustments:; - TEI: 2205 (392); - Other: Meal cost, study week, subject sex; Limitations:; - Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; NIH, USDA, Jenny Craig, Inc.
Ziylan, 2016^60^; RCT-Crossover, The Netherlands; Baseline N=120, Analytic N=120 (Attrition: 0%); Study objective: To assess the effect of size reduction or protein enrichment of readymade meals on protein and energy intakes at lunchtime and on subsequent ratings of satiety in vital older adults; Participant characteristics at baseline:; Adults, 65y or older; - [underlined: Age]: 70.5 (4.5) y; - [underlined: Female]: 47%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 27.2 (4.4) kg/m^2^; - [underlined: Physical activity]: Physical activity level: 68.4 (15.4); - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Not proficient in using the computer, participating in any other related research, not following a normal diet without dietary restrictions (including voluntary weight management restrictions), dislike the meal components | Intervention:; [underlined: Condition 1]: Normal size, lower protein (100%, 450 g, 432 kcal); [underlined: Condition 2]: Normal size, higher protein (100%, 450 g, 498 kcal); [underlined: Condition 3]: Reduced size, lower protein (89%, 400 g, 429 kcal); [underlined: Condition 4]: Reduced size, higher protein (89%, 400 g, 491 kcal); Duration: 1 meal (lunch) once a week for 4 weeks; Compliance: N/A; Outcomes and assessment methods:; Weighed food intake; Before and after test | Chicken Meal Energy intake; [underlined: Condition 1]: 382 (6) kcal; [underlined: Condition 2]: 423 (6) kcal; [underlined: Condition 3]: 375 (6) kcal; [underlined: Condition 4]: 441 (6) kcal; Condition 4 vs 1, 2, 3: P<0.05; Condition 2 vs 1, 3: P<0.05; Condition 1 vs 3: P=NS; Beef Meal Energy Intake; [underlined: Condition 1]: 341 (8) kcal; [underlined: Condition 2]: 427 (8) kcal; [underlined: Condition 3]: 340 (8) kcal; [underlined: Condition 4]: 416 (8) kcal; Condition 1 vs. 2, 4; P<0.05; Condition 2 vs. 3; P<0.05; Condition 3 vs. 5; P<0.05; Condition 1 vs. 3; P=NS and Condition 2 vs. 4; P=NS | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; Unclear why total energy served was similar between conditions, regardless of portion size and protein content; No preregistered data analysis plan; Funding:; Wageningen UR IPOP
Lewis, 2015^61^; RCT-Crossover, U.K.; Baseline N=33, Analytic N=33 (Attrition: 0%); Study objective: To investigate the impact of reducing breakfast portion size on subsequent energy intake, postprandial gastrointestinal hormone responses, and appetite ratings; Participant characteristics at baseline:; Adults, 18-60 y; - [underlined: Age]: 42.5 (2) y; - [underlined: Female]: 55%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 29.0 (0.4) kg/m^2^; - [underlined: Physical activity]: Vigorous PA (min/week): 65 (13); Moderate PA (min/week): 142 (21); Walking (min/week): 254 (30); - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Disordered eating (>11 on Eating Attitudes Test), depressive symptoms (>70 on Zung Depression Scale), smoking, excessive alcohol intake, weight loss/gain within last 3 months, or actively trying to lose/gain weight, medical conditions/medications potentially affecting appetite, inflammatory conditions, diabetes or fasting plasma glucose, pregnancy, breastfeeding, or planning pregnancy, extremely high levels of exercise, unable to eat study food, not regularly consuming breakfast (<3/week). | Intervention:; [underlined: Condition 1]: 100% Breakfast, Men: 791 kcal; Women: 607 kcal; [underlined: Condition 2]: 80% Breakfast, Men: 633 kcal; Women: 485 kcal; [underlined: Condition 3]: 60% Breakfast, Men: 475 kcal; Women: 363 kcal; Breakfast was compulsory, and followed by an ad libitum lunch (1978 kcal Men; 1518 kcalWomen) and snack (10 digestive biscuits); Duration: 2 meals and a snack (breakfast, followed by ad libitum lunch and snack) for 3 sessions; Compliance: 100% compliance; Outcomes and assessment methods:; Weighed food intake and weighed diet diary to record remainder of the day’s intake Before and after test meal; completed diet diaries | Lunch Energy intake, kcal; [underlined: Condition 1], 100%: 700.3 (48.5) kcal; [underlined: Condition 2], 80%: 681.9 (47.3) kcal; [underlined: Condition 3], 60%: 695.7 (42.8) kcal; Condition 1 vs. 2; P=0.429; Condition 2 vs. 3; P=0.547; Condition 1 vs. 3; P=0.850; Total Energy Intake (except breakfast), kcal; [underlined: Condition 1], 100%: 1762.4 (86.3) kcal; [underlined: Condition 2], 80%: 1808.3 (111.9) kcal; [underlined: Condition 3], 60%: 1771.8 (99.7) kcal; Condition 1 vs. 2; P=0.555; Condition 2 vs. 3; P=0.639; Condition 1 vs. 3; P=0.904; Total Energy Intake (with breakfast), kcal; [underlined: Condition 1], 100%: 2458.7 (94.4) kcal; [underlined: Condition 2], 80%: 2365.4 (117.4) kcal; [underlined: Condition 3], 60%: 2189.5 (104.4) kcal P=NR | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; UK Medical Research Council
Burger, 2011^62^; RCT-Crossover, U.S.; Baseline N=30, Analytic N=30 (Attrition: 0%); Study objective: To test possible mechanisms of the portion size effect, i.e., bite size and visual cues; Participant characteristics at baseline:; Adults, 18-60 y; - [underlined: Age]: 37.4 (11.1) y; - [underlined: Female]: 50%; - [underlined: Race and/or ethnicity]: Non-Hispanic White: 93%; Asian: 4%; Hispanic: 4%; - [underlined: Socioeconomic position]: Education: 16.1 (1.5) y; - [underlined: Anthropometry]: BMI: 25.9 (4.5) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Not willing to eat study foods, not able to read and understand English language at a 6th grade level, pregnancy, restrictive dietary practices, taste or visual impairment that could interfere with data collection | Intervention:; [underlined: Condition 1]: Small portion, 100%, 410 (10)g;; 1,255kcal; Not blindfolded; [underlined: Condition 2]: Small portion, 100%, 410 (10)g;; 1,255kcal; Blindfolded; [underlined: Condition 3]: Large portion, 200%, 820 (10)g;; 2,509kcal; Not blindfolded; [underlined: Condition 4]: Large portion, 200%, 820 (10)g;; 2,509kcal; Blindfolded; Duration: 1 meal (lunch) for 4 sessions; Compliance: Three males were excluded for being identified as plate cleaners (left <20g of the large portion in blindfolded condition); Outcomes and assessment methods:; Weighed food intake; Before and after test meals | Entree intake; Condition 1 vs. 3, main effect of portion size: 220 kcal (71.9g), p<0.05; Condition 2 vs. 4, main visual effect: NS (p=0.29); Total Energy Intake; Condition 1 vs. 3: +220 kcal from small to large portion, p<0.001; Condition 2 vs. 4: −102kcal for blindfolded, p<0.01; Complementary foods; NS | Model adjustments:; - TEI: NR; - Other: blindfolding; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; Colorado State University and USDA
Kral, 2004^63^; RCT-Crossover, U.S.; Baseline N=42, Analytic N=39 (Attrition: 7%); Study objective: To determine the combined effects of energy density and portion size on energy intake in women; Participant characteristics at baseline:; Women, age 20-45y in good health; - [underlined: Age]: 23.4 (1)y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 23.1 (0.4) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: All regularly consumed meals at regular intervals; Excluded from study or analysis: Men, smokers, dieting, in athletic training, pregnant/lactating, using medications known to affect food intake or appetite, not consuming regular meals (including breakfast), change in body weight (4.5kg) in previous 6 months, food allergies/restrictions, high scores for dietary restraint or depressive symptoms | Intervention:; [underlined: Condition 1]: 5.23kJ/g ED & 500g PS; [underlined: Condition 2]: 5.23kJ/g ED & 700g PS; [underlined: Condition 3]: 5.23kJ/g ED & 900g PS; [underlined: Condition 4]: 7.32kJ/g ED & 500g PS; [underlined: Condition 5]: 7.32kJ/g ED & 700g PS; [underlined: Condition 6]: 7.32kJ/g ED & 900g PS; Duration: All meals for 1 day x 6 weeks; Compliance: Three excluded, 1 for personal reasons after second session and 2 for not meeting minimum requirements for intake (>100g) and ratings of pleasantness of taste (>35mm) of manipulated entree; Outcomes and assessment methods:; Weighed food intake; Before and after each meal for all foods | Energy intake at lunch (kcal):; [underlined: Condition 1]: 398 (16); [underlined: Condition 2]: 472 (22); [underlined: Condition 3]: 482 (24); [underlined: Condition 4]: 526 (28); [underlined: Condition 5]: 560 (32); [underlined: Condition 6]: 620 (32); PS effect: P<0.0001; ED effect: P<0.0001; PS, ED interaction: P=0.27; Total daily energy intake (kcal):; [underlined: Condition 1]: 1671 (48); [underlined: Condition 2]: 1734 (50); [underlined: Condition 3]: 1763 (51); [underlined: Condition 4]: 1819 (65); [underlined: Condition 5]: 1829 (52); [underlined: Condition 6]: 1947 (56); PS effect: P=0.003; ED effect: P<0.0001; PS, ED interaction: P=NS; Energy intake at breakfast: P=NS; Energy intake at dinner: P=NS | Model adjustments:; - TEI: NR; - Other: Fixed factors: ED, PS, subjects were random; Limitations:; - Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; NIH
Haynes, 2020b^64^; RCT-Crossover, U.K.; Baseline N=39, Analytic N=30 (Attrition: 23%); Study objective: To test whether reductions to portion size would result in a significant reduction to daily energy intake when the resulting portion was visually perceived as ‘normal’ in size, but that a reduction resulting in a ‘smaller than normal’ portion size would cause immediate or later additional eating; Participant characteristics at baseline:; Adults, 18-60 y, BMI 22.5-32.5 kg/m^2^; - [underlined: Age]: 31.6 (10.3) y; - [underlined: Female]: 50%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: Education, bachelor’s degree or higher: 83%; - [underlined: Anthropometry]: BMI: 26.0 (2.3) kg/m^2^; Weight status: 37% normal weight, 63% overweight; - [underlined: Physical activity]: Moderate to vigorous physical activity: ~71 minutes per day; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Food allergies or intolerance, special dietary requirements, currently dieting, history of eating disorders, taking medication which affected appetite, not willing to consume each of the test foods, participation in a weight loss trial in last 4 weeks or portion size study in past 12 months | Intervention:; [underlined: Condition 1]: Small-normal lunch and dinner entrees (339 kcal/entrée, 5074 kcal/d); [underlined: Condition 2]: Normal lunch and dinner entrees (543 kcal/entrée, 5485 kcal/d); [underlined: Condition 3]: Large-normal lunch and dinner entrees (747 kcal/entrée, 5897 kcal/d); Duration: 3 conditions for 5 days (Monday-Friday); Compliance: Three participants did not commence study after enrollment, 6 withdrew for time commitments/schedule, disliked study food, illness, change in diet; Outcomes and assessment methods:; Weighed food intake; Before and after test meal | Total daily energy intake:; [underlined: Condition 1]: 2238 (490) kcal; [underlined: Condition 2]: 2448 (584) kcal; [underlined: Condition 3]: 2543 (592) kcal; P<0.001; Energy intake at lunch: entrée, additional entree, total:; [underlined: Condition 1]: 313 (13), 339 (196), 653 (203) kcal; [underlined: Condition 2]: 501 (56), 194 (190), 695 (221); [underlined: Condition 3]: 658 (97), 110 (140), 768 (210) kcal; Entree: P value NR; Additional entree intake: P<0.0001; Lunch: P<0.0001; Energy intake at dinner: entrée, additional entree, total:; [underlined: Condition 1]: 338 (22), 275 (154), 613 (162); [underlined: Condition 2]: 486 (79), 266 (147), 752 (181); [underlined: Condition 3]: 628 (119), 223 (149), 851 (214); Entree: P value NR; Additional entree intake: P=0.004; Dinner: P<0.0001 | Model adjustments:; - TEI: NR; Limitations:; - Did not account for those lost to follow-up in analyses; Funding:; Medical Research Council
Ellahi, 2022^65^; RCT-Crossover, U.K.; Baseline N=51, Analytic N=31 (Attrition: 39%); Study objective: To assess the efficacy, acceptance, and weight change of two guided/calibrated commercially available portion control tools (Utensil set and Crockery Set) used in free-living conditions; Participant characteristics at baseline:; Adults, women, 18 y and older, BMI >23 kg/m^2^, wanting to lose or maintain weight; - [underlined: Age]:; 18-29 y: 19%; 30-39 y: 32%; 40-49 y: 32%; 50+y: 16%; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: South Asian: 100%, Asian: 64.5%; Asian British: 35.5%; - [underlined: Socioeconomic position]: High school education: 58%, University education: 19%; Married: 83.9%; - [underlined: Anthropometry]: BMI: all >23 kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Males, already on a commercial weight loss diet, previously or presently using tools to measure portion size, suffering from active cancer, pregnant or lactating, or been diagnosed with an eating disorder, mental illness, or psychiatric disorder within the last 12 months that required active treatment | Intervention:; [underlined: Condition 1]: Portion-control utensil set; [underlined: Condition 2]: Portion-control crockery set; + general nutrition advice; Duration: 4 weeks for each condition; last 8 weeks participants preferred tools were used; Compliance: 61% retention rate. The majority reported that the utensils and the crockery set aided portion self-served, self-control, particularly of starchy foods, and aided learning about portions. For overall tool use, the crockery set scored higher in all areas of acceptance, ease of use, and perceived efficacy.; Outcomes and assessment methods:; 3-day food diaries; Baseline, week 3, 7, 15 (final week) | [underlined: Energy intake, mean]: 1504.7 kcal; [underlined: Baseline energy intake, mean]: 1521.3 kcal; [underlined: Week 16 energy intake, mean]: 1501.7 kcal; P=NS | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization concealment NR; Baseline energy intake was not reported, so unable to determine if tools were effective; Some concerns due to potential carryover effects; Did not account for missing data; Did not clearly report outcome data; No preregistered data analysis plan; Funding:; Tools were donated by Precise Portions Nutrition Control Systems and Jokari Healthy Steps; University of Chester
Robinson, 2015^66^; RCT-Parallel, U.K.; Baseline N=88, Analytic N=88 (Attrition: 0%); Study objective: To test whether the amount of food participants intended to consume was similar to the amount they subsequently ate; Participant characteristics at baseline:; Adults; - [underlined: Age]: ~33 (11)y; - [underlined: Female]: 50%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 25 (4) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: History of food allergy, disliking of study foods | Intervention:; [underlined: Group 1]: 100%, 75 g, 62 kcal; [underlined: Group 2]: 233%, 175 g, 145 kcal; All subjects were provided with a sandwich before being served dessert; Duration: 1 meal (lunch); Compliance: 100%; Outcomes and assessment methods:; Weighed food intake; Before and after meal | Energy intake (kcal), Males:; [underlined: Group 1]: 54.8 (13.9) kcal; [underlined: Group 2]: 111.7 (36) kcal; p<0.001; Energy intake (kcal), Females:; [underlined: Group 1]: 50.5 (17.4) kcal; [underlined: Group 2]: 59.5 (33.7) kcal p=0.28 | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization concealment NR; No preregistered data analysis plan; Funding:; Wellcome Trust
Marchiori, 2014^67^; RCT-Parallel, The Netherlands; Baseline N=121, Analytic N=110 (Attrition: 9%); Study objective: To test whether a brief mindfulness manipulation can prevent the portion size effect, and reduce overeating on unhealthy snacks when hungry; Participant characteristics at baseline:; Adults, university students; - [underlined: Age]: 20.9 (2.3) y; - [underlined: Female]: 71%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 22.3 (2.5) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Feel asleep during intervention, allergy to study foods, not following instructions | Intervention:; [underlined: Group 1]: Small portion (100%, 51 g, 10 cookies, 247.5 kcal), audio book; [underlined: Group 2]: Small portion (100%, 51 g, 10 cookies, 247.5 kcal), body scan; [underlined: Group 3]: Large portion (300%, 153 g, 30 cookies, 742.5 kcal), audio book; [underlined: Group 4]: Large portion (300%, 153 g, 30 cookies, 742.5 kcal), body scan; Duration: 1 meal (snack); Compliance: Seven excluded for sleeping during the study, 3 excluded for not following all the instructions, 1 excluded for an allergy to the study food; Outcomes and assessment methods:; Weighed food intake; Before and after test meal | Energy intake:; [underlined: Group 1+2 (100%)]: 139.53 (72.26) kcal; [underlined: Group 3+4 (300%)]: 222.77 (124.88) kcal; Portion size effect, P<0.001; (No significant effect of audio book vs body scan, P>0.05) | Model adjustments:; - TEI: NR; - Other: Results did not change when controlling for participant and food-related characteristics; Limitations:; - Methods for randomization concealment NR; No preregistered data analysis plan; Funding:; National Research Fund, Luxembourg; Netherlands Organization for Scientific Research
Reily, 2016^68^; RCT-Parallel, Australia; Baseline N=164, Analytic N=154 (Attrition: 6%); Study objective: To investigate whether contextual size information moderates the portion size effect, participants were served small or large portions of pasta for lunch in the presence or absence of contextual size information; Participant characteristics at baseline:; Adult women, first year psychology students or community members; - [underlined: Age]: 19.9 (2.84) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: Caucasian: 35.1%; Asian: 52.6%; Aboriginal or Pacific Islander: 0.6%; Other: 11.7%; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 22.1 (3.55) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Correctly identified study purpose, failed attention check, technical difficulties | Intervention:; [underlined: Group 1]: Small portion (100%, 300 g, 748 kcal), no context; [underlined: Group 2]: Large portion (200%, 600 g, 1496 kcal), no context; [underlined: Group 3]: Small portion (100%, 300 g, 748 kcal), label only; [underlined: Group 4]: Large portion (200%, 600 g, 1496 kcal), label only; [underlined: Group 5]: Small portion (100%, 300 g, 748 kcal), label + visual comparison; [underlined: Group 6]: Large portion (200%, 600 g, 1496 kcal), label + visual comparison; Duration: 1 meal (lunch); Compliance: Seven excluded for guessing study purpose, 2 excluded for failing the attention check, 1 excluded for technical difficulties; Outcomes and assessment methods:; Weighed food intake; Before and after test meal | Energy intake:; [underlined: Group 1, 3, 5]: 545 (165) kcal; [underlined: Group 2, 4, 6]: 688 (235) kcal; P<0.0001; There was no main effect of context on food intake | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; Australian Research Council
Raghoebar, 2019^69^; RCT-Parallel, Netherlands; Baseline N=140, Analytic N=132 (Attrition: 6%); Study objective: To explore the role of social (descriptive and injunctive) and personal portion size norms on the effect of portion size; Participant characteristics at baseline:; Adults, women; - [underlined: Age]: 21 (2) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: Dutch nationality: 95%; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 21.9 (2.3) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Not willing to eat study food, following a diet, allergies, intolerances, or dietary specific requirements, those who participated in the pilot study. | Intervention:; Group 1; [underlined: Condition 1]: 60%, 180g, 292 kcal; [underlined: Condition 2]: Self-serve family-style, 978g, 1584 kcal; Group 2; [underlined: Condition 1]: 180%, 540g, 875 kcal; [underlined: Condition 2]: Self-serve family-style, 978g, 1584 kcal; Side salad (10g or 30g) was also served, but salad consumption in kcal not provided; Duration: 2 sessions; Compliance: In the smaller PS condition: 1 was excluded for not following directions and 2 were excluded for guessing study aim; In the larger PS condition: 4 were excluded for not following directions and 1 for guessing study aim.; Outcomes and assessment methods:; Weighed food intake; Before and after test | [underlined: Group 1 (60%)]: 619.8 (169.6) kcal; [underlined: Group 2 (180%)]: 764.3 (195.9) kcal; P<0.001 | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; Groups were not exposed to both small and large portion sizes; Funding:; The Netherlands Organization for Scientific Research; Wageningen School of Social Sciences
Diliberti, 2004^70^; NRCT, U.S.; Baseline N=180, Analytic N=180 (100% PS: 89; 150% PS: 91) (Attrition: 0%); Study objective: To examine whether increasing the portion size of an entree affected energy intake at a restaurant meal; Participant characteristics at baseline:; Customers who purchased the pasta entree on study days and completed a short survey; mostly between 25-34 years and graduate students; - [underlined: Age]: 18-34 y; - [underlined: Female]: 54%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: 100% PS: 40% faculty/staff; 150% PS: 37% graduate students; - [underlined: Anthropometry]: Estimated overweight or obesity: 100% PS: 31%; 150% PS: 36%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Customer that did not select the pasta dish | Intervention:; [underlined: Group 1]: 100% (248g, 422 kcal); [underlined: Group 2]: 150% (377 g, 634 kcal); Entrée served with half tomato with pesto and white bread roll with butter; Duration: 1 meal (lunch) (10 test days over 5 months); Compliance: NA; Outcomes and assessment methods:; Weighed food intake; Before and after meal | Energy intake from the entree, kcal (mean (SE)):; [underlined: Condition 1]: 399 (3) kcal; [underlined: Condition 2]: 571 (8) kcal; P<0.0001; Energy intake from accompaniments, optional items, kcal (mean (SE):; [underlined: Condition 1]: 121 (9) kcal, 109 (23) kcal; [underlined: Condition 2]: 146 (8) kcal, 71 (16) kcal; Entree accompaniments: P<0.015; Optional items: P=NS; Energy intake from the meal, kcal (mean (SE)):; [underlined: Condition 1]: 630 (24)kcal; [underlined: Condition 2]: 789 (19) kcal; P<0.0001 | Model adjustments:; - TEI: NR; - Key confounders: Sex, Age, Education; - Other: Subgroup analysis: excluding those who ate the entire entree - PS effect remained significant (p<0.001). Mean meal EI increased for all subject characteristics (men, women, normal weight, overweight, age groups and university affiliations); Limitations:; - Not all key confounders accounted for; No preregistered data analysis plan; Funding:; NIH
Fisher (adults), 2007^21^; RCT-Crossover, U.S.; Baseline N=59, Analytic N=58 (Attrition: 2%); Study objective: To examine the effects of large portions on daily energy intake in 5y old Hispanic and African American children from low-income families; Participant characteristics at baseline:; Mother-child pairs, with 5y children attending Head Start; - [underlined: Age]: 30 (5) y; - [underlined: Female]: 100%; - [underlined: Race and/or ethnicity]: African American: 48%; Hispanic: 53%; - [underlined: Socioeconomic position]: Education, HS or less: 53%; Current employment: 55%; Low household food security: ~33%; - [underlined: Anthropometry]: BMI: 34 (9) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Presence of severe food allergies or chronic illnesses affecting food intake, dislike of the study foods, and self-reported previous diagnosis of maternal depression or eating disorders | Intervention; [underlined: Condition 1]: Reference portion (100%); [underlined: Condition 2]: Large portion (200%); All foods were provided to participants. The following foods varied in portion size:; Lunch: Macaroni and cheese; Afternoon snack: Apple juice, graham crackers; Dinner: Chicken, rice; Breakfast: Cereal; All other foods served were held constant across conditions.; Duration: 1 day (breakfast, lunch, dinner, snacks); Compliance: 1 exclude due to child’s loose tooth; Outcomes and assessment methods:; Weighed food intake; Before and after test meals | Morning snack: No PS manipulation, P=NS between conditions; Energy intake at lunch (macaroni and cheese, kcal; all other foods, kcal):; [underlined: Condition 1]: 363 (146) kcal; 289 (128) kcal; [underlined: Condition 2]: 424 (185) kcal; 251 (141) kcal; Manipulated food: P<0.05; All other foods: P=NS; Energy intake afternoon snack (apple juice, kcal; graham cracker, kcal):; [underlined: Condition 1]: 120 (45) kcal; 211 (79) kcal; [underlined: Condition 2]: 168 (87) kcal; 247 (137) kcal; Manipulated food: Apple juice, P<0.001;; Graham crackers, P=NS; Energy intake at dinner (chicken, kcal; rice, kcal; all other foods, kcal):; [underlined: Condition 1]: 279 (75) kcal; 109 (44) kcal; 401 (114) kcal; [underlined: Condition 2]: 367 (128) kcal; 128 (63) kcal; 365 (108) kcal; Manipulated food: Chicken, P<0.05; Rice, P=NS; All other foods: P<0.05; Evening snack: No PS manipulation, P=NS between conditions; Energy intake at breakfast: (cereal, kcal; all other foods, kcal):; [underlined: Condition 1]: 203 (95) kcal; 256 (75) kcal; [underlined: Condition 2]: 218 (103) kcal; 250 (83) kcal; Manipulated food: P=NS; All other foods: P=NS; Total energy intake:; [underlined: Condition 1]: 2819 (502) kcal; [underlined: Condition 2]: 2965 (616) kcal; P<0.01 | Model adjustments:; - TEI: NR; Limitations:; - Methods for randomization and concealment NR; No preregistered data analysis plan; Funding:; USDA

a Abbreviations: RCT: Randomized Controlled Trial; U.K.: United Kingdon; U.S.: United States; y: years; BMI: Body Mass Index; kg/m^2^: Kilograms per meters squared; kJ: kilojoule; kcal/d: kilocalories per day; SE: Standard Error; SD: Standard Deviation; NR: Not Reported; HHI: Household Income; HS: High school; iVR: Virtual reality; PA: Physical activity; mm: millimeters; TEI: Total Energy Intake; g: gram; Kcal: kilocalorie; fl. oz: Fluid ounce; NS: Not significant; NA: Not applicable; NRCT: non-randomized controlled trial; EAT: Eating Attitudes Test; PS: Portion size; ED: Energy density; SEP: socioeconomic position; Inc: incorporated; NIH: National Institutes of Health; NIFA: National Institute of Food and Agriculture; USDA: United States Department of Agriculture; JSPS: Japan Society for the Promotion of Science; TV: Television; $50k: $50,000; vs.: versus; ~: approximately; meals/d: meals per day; UR: University and Research

Table 19 Risk of bias for randomized controlled trials examining portion size and energy intake in adults and older adults^b^

Article | Randomization | Period and carryover effects | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Haynes, 2020a ^29^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Gough, 2021 ^30^ | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Cunningham, 2023b ^31^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Robinson, 2018 ^32^ | SOME CONCERNS | NOT APPLICABLE | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Rolls, 2010 ^33^ | SOME CONERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Langfield, 2023 ^35^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Rolls, 2004b ^36^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Cunningham, 2023a ^37^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Cahaydi, 2019 ^38^ | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Zuraikat, 2016 ^39^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Almiron-Roig, 2015 ^40^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Rolls, 2002 ^41^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Rosenthal, 2017 ^42^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Roe, 2016 ^43^ | SOME CONERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Levitsky, 2004 ^44^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Zuraikat, 2018a ^45^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Zuraikat, 2018c ^46^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Long, 2023 ^47^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Jeffery, 2007 ^48^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | SOME CONCERNS | HIGH
Rolls, 2006a ^49^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Rolls, 2006b ^50^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Kelly, 2009 ^51^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Rolls, 2007 ^52^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Levitsky, 2020 ^53^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Rolls, 2004c ^54^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Williams, 2014 ^55^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Shimpo, 2018 ^56^ | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Rolls, 2004a ^57^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Flood, 2006 ^58^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Zuraikat, 2018b ^59^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Ziylan, 2016 ^60^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Lewis, 2015 ^61^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Burger, 2011 ^62^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Kral, 2004 ^63^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Haynes, 2020b ^64^ | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Ellahi, 2022 ^65^ | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Robinson, 2015 ^66^ | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Marchiori, 2014 ^67^ | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Reily, 2016 ^68^ | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Raghoebar, 2019 ^69^ | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | LOW | SOME CONCERNS
Fisher, 2007a ^21^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

b Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 20 Risk of bias for non-randomized controlled trials examining portion size and energy intake in adults and older adults^c^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Berkowitz, 2016 ^34^ | CRITICAL | LOW | LOW | SERIOUS | LOW | MODERATE | LOW | VERY HIGH
Diliberti, 2004 ^70^ | SERIOUS | LOW | LOW | LOW | LOW | LOW | MODERATE | HIGH

c Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool (https://www.riskofbias.info/welcome/home/current-version-of-robins-i)” ( Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919. doi: 10.1136/bmj.i4919.27733354 )

Table 21 Evidence examining the relationship between pre-portioned foods and energy intake in young children, children, and adolescents^a^

Study and Population Characteristics | Intervention, Comparator, and Outcomes | Results | Confounding and Study Limitations
Marchiori, 2012^28^; RCT-Parallel, Belgium; Baseline N=85, Analytic N=77 (Attrition: 9%; Study objective: To examine the influence of altering the size of snack food (i.e., small vs large cookies) on short-term energy intake.; Participant characteristics at baseline: Children; - [underlined: Age]: 9.2 (2.5) y; - [underlined: Female]: 55%; - [underlined: Race and/or ethnicity]: Belgian nationality: 86%; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI percentile: 41 (20.9) %; - [underlined: Physical activity]: Exercise (h/wk): 3.8 (2); - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Presence of food allergies, overweight, weight problems, dieting behavior, food intake control in order to gain or lose weight, and lack of hunger | Intervention:; [underlined: Group 1]: Small cookie size, 36 half-sized (3.5g/each) (126 g total); [underlined: Group 2]: Large cookie size, 18 normal-sized (7g/each) (126 g total); Snack (cookies); Duration: 1 snack for 2 sessions; Compliance: Eight excluded based on exclusion criteria; Outcomes and assessment methods: Subtracted the number of cookies left from initial count.; Before and after test meal. | Energy intake from the snack:; Group 1 (small cookies): 274; Group 2 (large cookies): 342; p<0.05 | Limitations:; Methods for randomization and concealment NR; Concerns with validity and reliability of outcome assessment method; No preregistered data analysis plan; Funding:; National Research Fund, Luxembourg

a Abbreviations: RCT: Randomized controlled trial; y: years; NR: Not reported; BMI: body mass index; h/wk: hours per week; TEI: total energy intake; g: grams

Table 22 Risk of bias for randomized controlled trials examining pre-portioned foods and energy intake in young children, children, and adolescents^*^ * Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Article | Randomization | Period and carryover effects | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Marchiori, 2012 ^28^ | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | HIGH | SOME CONCERNS | HIGH

Table 23 Evidence examining the relationship between pre-portioned foods and energy intake in adults and older adults^a^

Study and Population Characteristics | Intervention, Comparator, and Outcomes | Results | Confounding and Study Limitations
French, 2014^71^; RCT-Parallel, U.S.; Baseline N=233, Analytic N=229 (Attrition: 2%); Study objective: To examine the effect of weekday exposure over 6 months to different lunch sizes on energy intake and body weight in a free-living sample of working adults; Participant characteristics at baseline: Adults; - [underlined: Age]: 42.6 (11.2) y; - [underlined: Female]: 67%; - [underlined: Race and/or ethnicity]: White: 69%; - [underlined: Socioeconomic position]: College degree or more: 52%; Income, $40-80k: 42%; >$80k: 37%; Married/living with partner: 59%; - [underlined: Anthropometry]: BMI: 29.8 (6.4) kg/m^2^; - [underlined: Physical activity]: Moderate/vigorous, mins/d: 27.5 (17.2); - [underlined: Smoking]: 100% nonsmokers; - [underlined: TEI]: Baseline: 2012 (679) kcal/d; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Smokers, non-English speaking, taking medications that affect appetite or body weight; unable to pick up lunches; allergic to or unwilling to eat study foods; currently on a diet to lose weight; eating disorder; planning to move; currently taking part in another research study; currently pregnant, nursing, or pregnant in the last 12 months | Intervention:; [underlined: Box lunch]: 400kcal, Mon-Fri; [underlined: Box lunch]: 800kcal, Mon-Fri; [underlined: Box lunch]: 1600kcal, Mon-Fri; [underlined: Control]: Habitual lunch intake; Lunch (sandwiches or salads); Duration: 6 months; Compliance: 91% of the lunches were picked up; Outcomes and assessment methods: 3, 24-hour recalls; Baseline, 1 month, 3 months, 6 months | Energy intake at lunch, total and rate of change:; [underlined: 400kcal box lunch]: 417 (30), −16.2; [underlined: 800kcal box lunch]: 557 (29), 0.5; [underlined: 1600kcal box lunch]: 636 (30), 16.9; [underlined: Control]: 492 (28), −7.9; [underlined: Between groups]: 1600kcal vs other conditions: P<0.05; 800kcal vs 400 kcal: P<0.05; [underlined: Within groups]:; Rate of change was significant for 400kcal and 1600 kcal, P<0.05; Energy intake, total daily and rate of change:; [underlined: 400kcal box lunch]: 1718 (70), −40.1; [underlined: 800kcal box lunch]: 1792 (68), −33.2; [underlined: 1600kcal box lunch]: 1996 (71), −0.66; [underlined: Control]: 1938 (66), −11.1; [underlined: Between groups]:; 1600kcal vs 400kcal, 800kcal: P<0.05; 1600kcal vs control: P=NS; 800kcal vs 400kcal, control: P=NS; 400kcal vs control: P<0.05; [underlined: Within groups]:; Rate of change was significant for 400kcal and 800 kcal, P<0.05 | Limitations:; Methods for randomization concealment NR, and concerns that randomization was not successful due to baseline differences; Minimal information provided about adherence to the study protocol; Unclear why rate of change outcomes were reported but mean data at the same timepoints were not; No preregistered data analysis plan; Funding:; NIH
Haire, 2014^72^; RCT-Parallel, U.S.; Baseline N=67, Analytic N=64 (Attrition: 4%); Study objective: To examine whether weight and restraint status influence the relationship between package size and consumption; Participant characteristics at baseline: Adults; - [underlined: Age]: ~24 (3) y; - [underlined: Female]: 47%; - [underlined: Race and/or ethnicity]: White: ~81%; - [underlined: Socioeconomic position]: Some college education: ~78%; - [underlined: Anthropometry]:; BMI:; ~22 kg/m^2^ ("normal weight" group); ~30 kg/m^2^ (overweight-obesity group); - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: High or low dietary restraint scores, does not like or allergic to the study food, health condition or medication use that affects eating or requires a therapeutic diet, unable to attend study visits, pregnant or breastfeeding | Intervention:; [underlined: Group 1]: Single serving packages, 22, 0.9 oz packages of pretzels; [underlined: Group 2]: Standard packages, 2, 10 oz packages of pretzels; Snack (pretzels); Duration: 4 days; Compliance: Three excluded for non-compliance (didn’t return pretzels or ate all the pretzels); Outcomes and assessment methods: Weighed food intake; Before and after 4 day test session | Energy intake from the snack:; [underlined: Condition 2 (Large package)]: 1150 (81) kcal; [underlined: Condition 1 (Control)]: 1030 (71) kcal P=0.04 | Limitations:; Subjects ate pretzels in a free-living setting, so unaccounted for non-compliance or measurement error is possible; Did not account for the rest of the diet; Funding:; No funding
Raynor, 2009^73^; RCT-Parallel, U.S.; Baseline N=24, Analytic N=19 (Attrition: 21%); Study objective: To examine the effects of providing breakfast foods in single-serving packages and non-portioned packages on energy intake of these foods during an 8-week behavioral weight-loss program; Participant characteristics at baseline: Adults; - [underlined: Age]: ~50.5 (9) y; - [underlined: Female]: 95%; - [underlined: Race and/or ethnicity]: White: 100%; Non-Hispanic: 100%; - [underlined: Socioeconomic position]: Some college or above: ~89%; NR; Married: ~63%; - [underlined: Anthropometry]: BMI: 31.8 (4) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: All regularly consumed breakfast 4 d/wk or more; Excluded from study or analysis: Do not consume breakfast at least 4 d/week, lactose-intolerant, allergic to or would not eat the provided foods, could not engage in physical activity, were participating in a weight-loss program and/or taking weight-loss medication or lost 5% of body weight during the past 6 months, unavailable for weekly meetings during the program, or were either pregnant, lactating, or <6 months postpartum, or planned to become pregnant during the investigation | Intervention:; [underlined: Group 1]: Single-serve portion breakfast + behavioral intervention; [underlined: Group 2]: Standard, non-portioned breakfast + behavioral intervention; All subjects received the same breakfast foods:; Cereal (22, 0.68oz boxes vs 1, 15oz box) and peaches (12, 4oz cans vs 3, 15oz cans) (weeks 1, 3, 5, 7); Applesauce (12, 4oz cans vs. 3, 15oz cans) and cheese (16, 1oz blocks vs 2, 10oz blocks) (weeks 2, 4, 6, 8); Breakfast (cereal and peaches; cheese and applesauce); Duration: 8 weeks; Compliance: Five excluded for scheduling conflicts; Outcomes and assessment methods:; Weighed food intake; Weekly | Energy intake per day from cereal and peaches (combined, cereal, peaches):; [underlined: Group 1]: 117.0 (3.2) kcal, 80.2 (2.9) kcal, 36.8 (0.3) kcal; [underlined: Group 2]: 143.5 (39.3), 106.3 (22.9) kcal, 37.2 (18.4) kcal; Combined, P<0.05; Cereal, P<0.01; Peaches, P=0.10; Energy intake per day from applesauce and cheese (combined, applesauce, cheese):; [underlined: Group 1]: 174.2 (13.5) kcal, 44.5 (0.6) kcal, 129.7 (13.4) kcal; [underlined: Group 2]: 199 (29.4) kcal, 59.3 (5) kcal, 139.6 (26.1) kcal; Combined, P<0.05; Applesauce, P<0.01; Cheese, P=0.10 | Limitations:; Methods for randomization and concealment NR; Did not describe dietary intake of non-study foods, so effects on total energy intake are not known; Power NR; Due to the free-living study design, compliance is not clear; No preregistered data analysis plan; Funding:; NIH
Reister, 2022^74^; RCT-Crossover, U.S.; Baseline N=31, Analytic N=30 (Attrition: 3%); Study objective: To examine whether snack package size and variety influence free-living snacking behavior in healthy adults; Participant characteristics at baseline: Adults; - [underlined: Age]: 23.6 (0.8) y; - [underlined: Female]: 93%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 22.8 (0.5) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% non-smokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: All regularly consumed snacks between lunch and dinner; Excluded from study or analysis: Diabetic or other disease, following or previously followed in the past 6 months a weight loss or other special diet, smokers, eating disorder, not habitual snackers | Intervention:; [underlined: Condition 1]: Control, provided with commonly consumed snacks; [underlined: Condition 2]: Large package, provided with snacks in larger package sizes; Subjects were provided with all food consumed over each 3-d session (compulsory breakfast, lunch, and dinner); Snack (variety); Duration: 3 days for 3 sessions; Compliance: One excluded for snack intake data that was an extreme outlier; Outcomes and assessment methods:; Weighed food intake; Before and after each 3-day session | Energy intake from the snack:; [underlined: Condition 2]: 1150 (81) kcal; [underlined: Condition 1]: 1030 (71) kcal; P=0.04 | Limitations:; Methods for randomization and concealment NR; Did not describe compliance; Funding:; Sabra Dipping Company, LLC
Rolls, 2017^75^; RCT-Parallel, U.S.; Baseline N=186, Analytic N=151 (Attrition: 19%); Study objective: To test whether the efficacy of a behavioral weight-loss program was improved by incorporating either of the two portion-control strategies instead of standard advice about eating less; Participant characteristics at baseline: Adults; - [underlined: Age]: 50 (11) y; - [underlined: Female]:100%; - [underlined: Race and/or ethnicity]: White: 98%; African American: 1%; More than 1 race: 1%; Hispanic: 1% (Not Hispanic: 99%); - [underlined: Socioeconomic position]: Some college: 30%, College degree: 31%, Graduate degree: 25%; - [underlined: Anthropometry]: BMI: ~34 kg/m^2^; - [underlined: Physical activity]: Steps per day: ~6500; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: Blood pressure >160/100 mm Hg, reported a weight change >4.5 kg in the past 3 months, had a medical condition that precluded participation or that limited the physical activity, were following a special diet or weight-loss program, were pregnant or lactating, scored >19 on the Eating Attitudes Test or >25 on the Beck Depression Inventory, did not complete all activities during 2-week run-in | Intervention:; [underlined: Pre-portioned foods]: Instructed to structure their meals and to learn appropriate food portions by using pre-portioned foods, such as individual servings of main dishes, side dishes, snacks, yogurt and whole fruits. Participants were instructed to eat pre-portioned main dishes daily for lunch and dinner during months 1–3 of the trial and were encouraged to continue this practice subsequently. Given pre-paid vouchers for single-serving main dishes (14 vouchers per week in month 1); [underlined: Portion selection]: Instructed to choose food portions based on ED in order to eat satisfying portions of low-ED foods and to control portions of higher-ED foods. Were provided with portion-selection tools (food scale, household measures, placemat for appropriate portions, card for portion estimations using common objects); [underlined: Standard advice]: Follow dietary guidelines that emphasized eating less while making healthy choices from all food groups; Self-selected foods; Duration: 12 months; Compliance: Thirty-five were lost to follow-up at 1 year; Outcomes and assessment methods:; 3, 24-hour recalls; Baseline, 3 months | Change in energy intake from baseline to 3mo, all groups combined:; -387 (686) kcal per day; Within groups, P<0.0001; Change in energy intake (kcal), baseline vs. 3 month, between groups:; [underlined: Standard advice]: 1968 (661) kcal vs. 1518 (495) kcal; [underlined: Portion selection]: 1799 (635) kcal vs. 1539 (525) kcal; [underlined: Pre-portioned]: 1887 (593) kcal vs. 1458 (487) kcal; Between groups, P=NS | Limitations: None; Funding:; NIH; Food vouchers from ConAgra Foods, Inc, Nestlé USA.
Devitt, 2004^76^; RCT-Crossover, U.S.; Baseline N=26, Analytic N=20 (Attrition: 23%); Study objective: To examine the effects of food unit size (FU) and energy density (ED) on food consumption; Participant characteristics at baseline: Adults; - [underlined: Age]: 22.6 (5.8) y; - [underlined: Female]: 45%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 25.3 (4.3) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: All regularly consumed 3 meal/d; Excluded from study or analysis: Did not like study foods, did not follow a typical meal pattern of 3 meal/d | Intervention:; [underlined: Condition 1]: Small food unit, low energy density; [underlined: Condition 2]: Small food unit, high energy density; [underlined: Condition 3]: Customary food unit, low energy density; [underlined: Condition 4]: Customary food unit, high energy density; Entrees (omelet, wraps, pizza); Duration: 1 day (breakfast, lunch, dinner); Compliance: Six excluded for not completing all sessions; Outcomes and assessment methods:; Weighed food intake; Before and after each test meal | Energy intake at breakfast:; [underlined: Condition 1]: 299 (22) kcal; [underlined: Condition 2]: 655 (38) kcal; [underlined: Condition 3]: 378 (30) kcal; [underlined: Condition 4]: 595 (53) kcal; Main effect of unit size: P=NS; Main effect of ED: P=0.0003; Energy intake at lunch:; [underlined: Condition 1]: 273 (25) kcal; [underlined: Condition 2]: 613 (70) kcal; [underlined: Condition 3]: 229 (33) kcal; [underlined: Condition 4]: 595 (98) kcal; Main effect of unit size: P=NS; Main effect of ED: P=0.045; Energy intake at dinner:; [underlined: Condition 1]: 819 (62) kcal; [underlined: Condition 2]: 983 (100) kcal; [underlined: Condition 3]: 1004 (340) kcal; [underlined: Condition 4]: 1074 (76) kcal; Main effect of unit size: P=NS; Main effect of ED: P=NS; Total daily energy intake:; [underlined: Condition 1]: 1391 (64) kcal; [underlined: Condition 2]: 2250 (147) kcal; [underlined: Condition 3]: 1611 (98) kcal; [underlined: Condition 4]: 2264 (168) kcal; Main effect of unit size: P=NS; Main effect of ED: P=0.008 | Limitations:; Methods for randomization and concealment NR; Did not describe whether assignments were counterbalanced; Did not describe compliance; No preregistered data analysis plan; Funding:; NR
Raynor, 2007^77^; RCT-Parallel, U.S.; Baseline N=40, Analytic N=28 (Attrition: 30%); Study objective: To examine the independent effects of package unit size and amount of food on intake; Participant characteristics at baseline: Adults; - [underlined: Age]: 20 (1.6) y; - [underlined: Female]: 57%; - [underlined: Race and/or ethnicity]: White: 68%; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: ~23 (2) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: 100% non-smokers; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: All regularly snack; Excluded from study or analysis: Not healthy, smokers, following a weight loss diet, athlete in training, pregnant, breastfeeding, health condition or medication that affects eating or requires diet therapy, consumed snack foods <3 times/week, allergies to or dislike for study foods, restrained eater, binge eater | Intervention:; [underlined: Group 1]: Small unit, small amount (5 bags of chips, 5 bags of crackers, 6 bags of cookies, 5 bags of candies), 4320 kcal; [underlined: Group 2]: Small unit, large amount (10 bags of chips, 9 bags of crackers, 12 bags of cookies, 11 bags of candies), 8820 kcal; [underlined: Group 3]: Large unit, small amount (1 bag of chips, 1 bag of crackers, 1 bag of cookies, 1 bag of candies), 4374 kcal; [underlined: Group 4]: Large unit, large amount (2 bags of chips, 2 bags of crackers, 2 bags of cookies, 2 bags of candies), 8748 kcal; Small and large unit conditions provided the same g weight of food, in different package/unit sizes; Small and large amount conditions provided larger portions of the same foods; Snack (chips, cookies, crackers, candy); Duration: 3-day period for 1 snack session; Compliance: Six excluded for not attending a session, 4 rated the foods poorly, 2 had a BMI >30 kg/m^2^; Outcomes and assessment methods:; Weighed food intake; Before and after the 3-day session | Energy intake from the snack:; [underlined: Portion size effect (Group 1/3 vs 2/4]): 5028.1 (2596.1) vs. 2782.2 (1174.5) kcal, P<0.01; [underlined: Unit size effect (Group 1/2 vs 3/4)]: 4026.8 (2313.1) kcal vs. 3783.4 (2335.1) kcal, P=NS; Unit size/amount interaction, P=NS | Limitations:; Methods for randomization and concealment NR; Baseline differences between groups in mean BMI may suggest problems with randomization; Did not account for consumption of other foods or snacking context during the 3-day session; Did not account for those who did not complete the study; Underpowered to detect a unit size effect; No preregistered data analysis plan; Funding:; NIH
van Kleef, 2014^78^; RCT-Parallel, The Netherlands; Baseline N=165, Analytic N=NR (Attrition: NR); Study objective: To explore how perceptions of impulsivity mediate consumption effects of unit size.; Participant characteristics at baseline: Adults; - [underlined: Age]: 21.0 (2.4) y; - [underlined: Female]: 63%; - [underlined: Race and/or ethnicity]: NR; - [underlined: Socioeconomic position]: NR; - [underlined: Anthropometry]: BMI: 21.6 (2.4) kg/m^2^; - [underlined: Physical activity]: NR; - [underlined: Smoking]: NR; - [underlined: TEI]: NR; - [underlined: Habitual diet at baseline]: NR; Excluded from study or analysis: NR | Intervention:; [underlined: Group 1]: Large unit, no wrapper, 3 chocolate bars, 153 g, 684 kcal; [underlined: Group 2]: Large unit, wrapper, 3 chocolate bars, 153 g, 684 kcal; [underlined: Group 3]: Small unit, no wrapper, 15 chocolate bars, 150g, 675 kcal; [underlined: Group 4]: Small unit, wrapper, 15 chocolate bars, 150g, 675 kcal; Snack (chocolate bars); Duration: 1 snack session; Compliance: NR; Outcomes and assessment methods:; Weighed food intake; Before and after the test session | Energy intake from the snack:; [underlined: Group 1]: 247.4 (108.9) kcal; [underlined: Group 2]: 197.3 (118.8) kcal; [underlined: Group 3]: 153.7 (91.1) kcal; [underlined: Group 4]: 186.1 (97.8) kcal; Main effect of unit size: P<0.01 (220.0 kcal vs. 170.5 kcal); Main effect of wrapper: P=0.44; Interaction effect of unit size and packaging: P<0.01, the unit size effect was primarily due to the unwrapped chocolate | Limitations:; Methods for randomization and concealment NR; Participant inclusion and exclusion criteria not described; Did not describe compliance; No preregistered data analysis plan; Funding:; NR

a Abbreviations: RCT: Randomized controlled trial; y: years; $50k: $50,000; NR: Not reported; BMI: body mass index; kg/m^2^: kilograms per meters squared; mins/d: minutes per day; kcal/d: kilocalories per day; kcal: kilocalories; NS: Not significant; NIH: National Institutes of Health; oz: ounces; d/wk: days per week; TEI: total energy intake; mo: month; wks: weeks; mm HG: millimeters of mercury; kg: kilograms; ED: Energy density; U.S./USA: United States/United States of America; Mon-Fri: Monday through Friday; LLC: Limited liability company; Inc.: Incorporated; meal/d: meal per day

Table 24 Risk of bias for randomized controlled trials examining pre-portioned foods and energy intake in adults and older adults^b^

Article | Randomization | Period and carryover effects | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
French, 2014 ^71^ | HIGH | NOT APPLICABLE | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Haire, 2014 ^72^ | LOW | NOT APPLICABLE | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS
Raynor, 2009 ^73^ | SOME CONCERNS | NOT APPLICABLE | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Reister, 2022 ^74^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS
Rolls, 2017 ^75^ | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Devitt, 2004 ^76^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Raynor, 2007 ^77^ | SOME CONCERNS | NOT APPLICABLE | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Van Kleef, 2014 ^78^ | SOME CONCERNS | NOT APPLICABLE | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | SOME CONCERNS

b Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )