# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for this systematic review and a systematic review assessing the relationship between portion size and pre-portioned foods and growth, body composition, and risk of obesity.^†^ The intervention/exposures of interest for this review, portion size and pre-portioned foods, were considered separately. The literature search (Appendix 2) yielded 6,050 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 4,775 titles, 883 abstracts, and 304 full-texts articles. Reasons for full-text exclusion are in Appendix 3. One additional article was identified from the manual search. The body of evidence included 78 articles:

- [underlined: Portion size in young children, children, and adolescents]: 27 articles
- [underlined: Pre-portioned foods in young children, children, and adolescents]: 1 article
- [underlined: Portion size in adults and older adults]: 43 articles
- [underlined: Pre-portioned foods in adults and older adults]: 8 articles
- [underlined: Portion size in individuals during pregnancy]: 0 articles
- [underlined: Pre-portioned foods in individuals during pregnancy]: 0 articles
- [underlined: Portion size in individuals during postpartum]: 0 articles
- [underlined: Pre-portioned foods in individuals during postpartum]: 0 articles

† Raynor HA, Gardner CD, Anderson CAM, Andres A, Fisher JO, Giovannucci E, Hoelscher DM, Jernigan VBB, Odoms-Young A, Palacios C, Stanford FC, Fultz, AK, Obbagy J, Butera G, Higgins M, Terry N. Portion Size and Growth, Body Composition, and Risk of Obesity: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR17

Figure 2 Literature search and screen flowchart

The literature search (Appendix 2) yielded 6,050 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 4,775 titles, 883 abstracts, and 304 full-texts articles. Reasons for full-text exclusion are in Appendix 3. One additional article was identified from the manual search. The body of evidence included 78 articles.

## Portion size in young children, children, and adolescents

### Description of the evidence

Twenty-seven articles met inclusion criteria to examine the relationship between portion size and energy intake in young children, children, and adolescents. One article conducted two experiments allowing for a total of 28 interventions to be examined in this body of evidence.^1^ Of the 28 interventions, 25 were crossover randomized controlled trials,^1–25^ 2 were parallel arm randomized controlled trials,^1,26^ and 1 was a non-randomized controlled trial.^27^ Evidence for portion size and energy intake in young children, children, and adolescents is summarized in Table 15.

#### Population

Twenty-three articles were conducted in the U.S.,^3–7,9–25^ 2 in the U.K.,^8,26^ 1 in Belgium,^1^ and 1 in Singapore.^27^ The total analytic sample sizes ranged from N=17 to N=125. Children enrolled in the trials were between the ages of 2 and 9 years with the majority between 4 to 5 years of age. Studies included approximately 46-61% female participants, however, there were 3 studies that included predominately male participants.^4,7,23^ Children ranged between the 50-70^th^ percentile for body mass index for age. Parents reported high levels of education and annual household incomes. The majority of studies enrolled predominantly non-Hispanic White participants, though 6 studies did include a majority of participants who identified as Black/African American^12,13,15,20,21^ and/or Hispanic or Latino,^14^ and 4 studies reported approximately 30%^4,17,19^ or predominately Asian.^27^

#### Intervention/exposure and comparator

Most interventions (N=23) tested the effects of varying portion sizes of one meal or snack, with the number of test conditions ranging from 3 to 12.^1–3,6,8–20,22–25,27^ Articles varied in terms of duration, and in how many and which foods were varied in portion size. Most articles, 17 of 23, examined portion size effects at a single meal; 8 of 23 articles manipulated the portion size of the main entrée with fixed amounts of other components at the meal, 5 of 23 articles manipulated portion sizes of all components of the meal, 10 of 23 manipulated portion sizes of snacks, vegetable side dishes, first courses, or the beverage only. Five of 28 studies evaluated effects of portion size beyond a single meal, with durations ranging from 1 day to 8 weeks. One of the five articles manipulated 2 lunches per week for 8 weeks.^4^ Another tested the effects of portion size for 5 days by increasing the portion size of vegetables and fruits offered at meals and snacks with either no change in other foods or simultaneously decreasing the portion size of all other foods for 5 days.^5^ Another study increased all foods at meals and snacks by 50% for 5 days.^7^ One study tested a snack reduction for 3 weeks^26^ while another study increased the portion sizes of entrees at lunch, dinner, and breakfast as well as an afternoon snack over 1 day.^21^

#### Outcome

The main outcome of interest was energy intake. Energy intake was assessed most often by weighing food intake before and after test meals. Two articles assessed energy intake differently, which included a plate waste method measured after the meal (method not described in detail)^4^ and 4-day weighed food diaries assessed weekly.^26^ Most articles reported energy intake of the manipulated foods and total energy intake of the manipulated foods combined with additional meal components (side dishes, beverages).^2,3,6,8,10,12,14–16,19,20,23,24^ Fewer articles reported energy intake of a snack,^1,11,18,26^ or total meal energy intake only.^13,22,25,27^ Of the articles that evaluated portion size effects beyond a single meal, one study reported entrée energy intake, energy intake from dessert, and total lunch energy intake.^4^ Another reported energy intake across 5 days including energy intake from food only, milk only, and food and milk.^5^ One study reported daily energy intake including all food/meal components.^7^ One study reported weekly snack energy intake^26^ and another reported energy intakes at meals, snacks, and total daily energy intake.^21^

### Synthesis of the evidence

Evidence was synthesized by the types of foods of which portion size was manipulated: energy dense food, vegetables and fruits, and all foods. Effects on energy intake were examined by considering energy intake from the portion size manipulated food, effects on other foods, and effects on total energy intake.

#### Energy dense food

There were 10 articles that manipulated the portion size of energy dense foods (e.g., macaroni and cheese, sandwiches, graham crackers)^1,4,8,11,16,21–25^ and of these, 8 showed increases in energy intake of the energy dense food that was manipulated.^1,8,11,16,21–24^ Of the remaining 2 articles, one reported null results for increased energy intake of the energy dense food (i.e., lunch entrée)^4^ and in the other, increases in energy intake of the energy dense macaroni and cheese was observed for 5-year-old children but not for 3-year-old children.^25^ Among the 10 articles, increasing the portion size of energy dense food had limited effects on intake of other foods served with them. Six articles found null effects of increasing portion size of an energy dense entrée on energy intake of other foods served at the meal.^4,8,11,21,22,24^ One article found a null effect for milk while energy intake of the vegetable and side roll decreased.^16^ Another article found that increasing the portion size of an energy dense entrée lead to increased energy intakes of other foods served with the entrée among 5–6-year-old and 8–9-year-old children but not among children 2-3 years of age.^23^ Most of these single meal studies demonstrated increases in total energy intake of the meal,^8,16,22–24^ with one study demonstrating increases in total daily energy intake.^21^ One article manipulated the portion size of a beverage served at the meal and found no effects on meal energy intake.^11^ Another study found that increases to portion size of an energy dense entrée increased meal energy intake for 5-year-old children but did not affect meal energy intake among 3-year-old children.^25^

#### Vegetables and fruits

There were 6 articles that manipulated portion sizes of vegetables and fruits, and all found significant increases in both food and energy intake of the manipulated vegetable and fruit.^5,6,15,17,19,20^ However, in the case of one article, the increase in energy intake was only found for the fruit (applesauce) side, not the vegetables (broccoli or carrots).^20^ Three articles found an effect of increasing vegetable and/or fruit portion sizes on energy intake of other foods served at the meal.^15,17,20^ One found a decrease in entrée energy intake with no effect on the milk served at the meal.^20^ Another study reported a decrease in pasta entrée energy intake when double portions of vegetables and fruits were served.^15^ When smaller compared to larger servings of a vegetable soup and when serving the vegetable soup as a first course compared to not, there was a decrease in entrée energy intake as well as increase in vegetable consumption at the meal; however, there was also a subsequent increase in energy intake during the afternoon snack.^17^ In most articles, increasing vegetable and fruit portion sizes had non-significant effects on meal energy intake, indicating that increasing vegetable and fruit portion sizes at meals produced increases in intakes of those foods without appreciable effects on total energy intake at the meal. One article found that serving a vegetable soup as first course resulted in reduced energy intake at the meal compared to a no soup control, however, when energy intakes of the soup plus meal were combined, the results were no longer significant.^17^ Another article which doubled portion size and increased energy density of vegetables at the meal found an increase in meal energy intake, and while it was found to be statistically significant, the increase amounted to 13 kilocalories or a 5% increase.^6^ Only 1 article reported results for daily total energy intake, which decreased over 5 days in addition to lower energy intake from food per day and food and milk per day when the portion size of vegetables and fruits were increased while simultaneously decreasing the portion size of all other food served.^5^ In this same study when the portion size of vegetables and fruits was increased with no adjustments made to the rest of the meal, energy intake increased for food only, food and milk, and energy intake across 5 days.^5^

#### All foods

Seven articles manipulated the portion size of all foods served at the meal or throughout the day. Of the articles reporting effects on children’s consumption of energy dense foods, all found increases in energy intake and gram weight intake of the energy dense foods.^2,3,7,10,12,13,27^ Effects of increasing portion sizes of all foods at a meal or throughout the day on vegetable and fruit intakes were variable. One article found no change in intakes of vegetables and fruits when all foods at the meal were increased in portion size.^2^ However, it is important to note that while vegetable energy intake was unchanged across portion size conditions, there was a trend for increased fruit intake.^2^ Another article reported no change in energy intakes of the vegetables and fruits associated with the meal.^12^ Two articles reported increased energy intakes for fruits at the meal but not for vegetables.^7,10^ One article found increased energy intakes for both vegetables and fruits^3^ while the remaining articles^13,27^ did not report effects associated with vegetables and fruits. All 7 articles reported increased meal energy intakes when the portion size of all foods at the meal were increased. One article reported on daily energy intake which also increased across portion size manipulations.^7^

The remaining articles in this body of evidence manipulated portion sizes of both energy dense foods and vegetables and fruits,^1,18,26^ with 1 article manipulating the portion size of milk.^9^ One study found increased energy intakes of both the energy dense snack (pudding) and fruit snack (applesauce) which subsequently increased overall snack energy intake.^18^ Another study showed that increasing the portion size of an energy dense snack (cookies) resulted in increased energy intake but not when a vegetable (carrots) was served as a snack.^1^ Total snack energy intakes were not reported. One study tested snack reduction for a week and found no change in snack energy intake compared to baseline^26^. In the article that tested varying portion sizes of milk, milk energy intake increased with increased portion size, however, there was no effect on other foods or meal energy intake.^9^

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed 3 conclusion statements to answer the question, “What is the relationship between portion size and energy intake?” based on their review of the body evidence on portion sizes served to young children, children, and adolescents (Table 4, Table 5, Table 6).

Table 4 Conclusion statement and grade for portion size and energy intake in young children, children, and adolescents

Conclusion Statement | Serving larger portions of energy dense foods increases energy intake in children. This conclusion statement is based on evidence graded as strong.
Grade | Strong
Body of Evidence | Twenty-seven articles comprising 28 interventions; 25 RCT-crossover, 2 RCT-parallel, 1 NRCT
Consistency | Few concerns with consistency. Strengths demonstrated by consistent direction and magnitude of effects with similar study designs and methods used.
Precision | Few concerns with precision. Strengths demonstrated by studies with sufficient power.
Risk of bias | Some concerns with risk of bias due to a lack of information about randomization methods and the potential for selective reporting of results.
Directness | Few concerns with directness. The studies were directly designed to examine the effects of portion size and energy intake.
Generalizability | Some concerns with generalizability due to a lack of diversity for study participants with regards to race and ethnicity and socioeconomic position.

Table 5 Conclusion statement and grade for portion size and energy intake in young children, children, and adolescents

Conclusion Statement | Serving larger portions of vegetables and fruits increases intake of those foods without increasing energy intake in children. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | Six articles; all RCT-crossover; - An additional 3 articles examined both high energy dense food and vegetables and fruits on energy intake, although vegetables and fruits were not the primary purpose; 2 RCT-crossover, 1 RCT-parallel
Consistency | Few concerns with consistency. Strengths demonstrated by consistent direction and magnitude of effects with similar study designs and methods used.
Precision | Some concerns due to fewer number of studies directly testing portion size of vegetables and fruits, however, those that did were sufficiently powered.
Risk of bias | Some concerns with risk of bias due to a lack of information about randomization methods and the potential for selective reporting of results.
Directness | Few concerns with directness. The studies were directly designed to examine the effects of vegetable and fruit portion sizes and energy intake.
Generalizability | Some concerns with generalizability due to a lack of diversity for study participants with regards to race and ethnicity and socioeconomic position.

Table 6 Conclusion statement and grade for portion size and energy intake in young children, children, and adolescents

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between portion size and energy intake in young children and adolescents because there is no evidence available.
Grade | Grade not assignable
Body of Evidence | 0 articles
Rationale | There is not enough evidence available to answer this question.

#### Assessment of the evidence

The body of evidence underlying these conclusion statements includes 25 crossover randomized controlled trials, 2 parallel arm randomized controlled trials, and 1 non-randomized controlled trial. All articles were conducted in children, and no articles were identified that examined portion size and energy intake in young children or adolescents. The strength of the evidence was graded based on an assessment of 5 grading elements, as described below. Publication bias was also considered, and there were some concerns with publication bias for this body of evidence. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. In addition, while few studies with null findings were identified in the literature, several of the included articles did report both statistically significant and non-significant results.

##### Consistency

The findings reported by the articles in this body of evidence were consistent in the direction and magnitude of effect. Results consistently showed that serving larger portion sizes led to increased intakes, such that when energy dense foods were consumed, total energy intake increased. Conversely, when larger portions of vegetables and fruits were served to children, intakes increased, but because of the lower energy density of those foods, the increased intake did not lead to increased total energy intakes.

##### Precision

This body of evidence demonstrated precision due to an adequate number of studies conducted in children, and while there were fewer studies that examined the effects of portion sizes for vegetables and fruits, those that did were sufficiently powered.

##### Risk of bias

These studies had some concerns with risks of bias including lack of detail on randomization and concealment methods, limited detail on missing data and those lost to follow-up, and no preregistered protocol or data analysis plans. Despite these risks of bias, however, there was little indication that randomization was not effective or that selective reporting occurred. There were a few studies with higher risks of bias due to concerns related to the description of outcome measurements, potential deviations from intended intervention, not accounting for compliance or consumption of other foods, not accounting for all key confounders, and no power calculations (Table 16 and Table 17).

##### Directness

The studies in this body of evidence were directly designed to test the relationship between portion size and energy intake in children.

##### Generalizability

The body of evidence is generalizable to children in the U.S. regarding both participant characteristics and the interventions and outcomes studied. Articles that provided details on participants’ race and ethnicity and socioeconomic position tended to enroll a majority of White, non-Hispanic children from higher socioeconomic positions. However, there were some studies conducted in populations reflecting greater diversity with respect to these characteristics, and the results of those studies were consistent.

## Pre-portioned foods in young children, children, and adolescents

### Description of the evidence

One article met inclusion criteria to examine the relationship between pre-portioned foods and energy intake in young children, children, and adolescents.^28^ The article was a parallel randomized controlled trial. Evidence for pre-portioned foods and energy intake in young children, children, and adolescents is summarized in Table 21.

#### Population

This study was conducted in Belgium with a sample size of N=77 children with a mean age of ~9 years including both males and females (55% female). Children were approximately in the 40^th^ percentile for BMI-for-age. Socioeconomic position was not reported and 86% of the children were of Belgian nationality.^28^

#### Intervention/exposure and Comparator

This study evaluated the effects of cookie size (and number) on energy intake, holding the total amount (weight) offered constant. Small cookies (N=40; 36 half-sized, 3.5g/each, 126g total) were served compared to larger cookies (N=37; 18 normal size, 7g/each, 126g total).^28^ Children always received the same sized cookies per session based on their randomized placement.

#### Outcome

The study measured energy intake as its primary outcome. Energy intake was measured via visual estimation of the cookies before and after the test.^28^

### Synthesis of the evidence

The results of this study showed that children served the large cookies consumed 68 kilocalories more compared to the children served smaller cookies.^28^

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between portion size and energy intake?” based on their review of the body evidence on serving pre-portioned foods to young children, children, and adolescents (Table 7). The body of evidence includes 1 parallel randomized controlled trial with a high risk of bias for measurement of the outcome related to visual estimation as opposed to weighing (Table 22). Publication bias was unable to be evaluated, and it is unknown if the influence of publication bias contributed to the lack of articles available for inclusion in this body of evidence. The evidence was insufficient to develop a conclusion statement.

Table 7 Conclusion statement and grade for pre-portioned foods and energy intake in young children, children, and adolescents

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between pre-portioned foods by young children, children, and adolescents and energy intake because there is not enough evidence available.
Grade | Grade not assignable
Body of Evidence | One article; RCT-Parallel
Rationale | There is not enough evidence available to answer this question.

## Portion size in adults and older adults

### Description of the evidence

Forty-three articles met inclusion criteria to examine the relationship between portion size and energy intake in adults and older adults. Several articles included multiple experiments, so there were 51 interventions examined in the 43 articles.^29–35^ Of the 51 experiments, 39 were crossover randomized controlled trials, ^21,29,31,33,35–65^ 9 were parallel arm randomized controlled trials,^30,32,66–69^ and 3 were non-randomized controlled trials.^34,70^ Evidence for portion size and energy intake in adults and older adults is summarized in Table 18.

#### Population

Thirty studies were conducted in the U.S.,^21,31,33,34,36,37,39,41–50,52–55,57–59,62,63,70^ 14 in the U.K.,^29,30,32,35,40,61,64–66^ 3 in the Netherlands,^60,67,69^ and 1 each in New Zealand,^38^ Japan,^56^ Australia,^68^ and Ireland.^51^ The total analytic sample sizes ranged from N=13 to N=154 with a few larger studies conducted in worksite/college cafeterias. The mean age range of study participants was from 20 to 71 years, with most participants between 20 to 40 years of age. Most articles enrolled both women and men, with 2 studies in men only^32,56^ and 18 studies in women only.^21,31,32,35,40,43,45,46,48,50,54,55,63,65,68,69^ Participants had a mean body mass index (BMI) between 22 to 34 kg/m^2^ with most articles reporting BMI between 23-26 kg/m^2^. Fifteen articles provided information on socioeconomic position with most only describing education and household income. Within those articles, most participants reported a college degree or higher and annual household incomes greater than $50,000 per year. The majority of articles did not report information on race or ethnicity and in those that did, 13 reported to be predominately White^31,35,37,42,45–48,53,59,62^ and 1 article each with predominately African American (48%) or Hispanic (52%) participants,^21^ South Asian (100%),^65^ majority Asian (53%),^68^ likely majority Japanese,^56^ and majority Dutch (95%).^69^ Overall, subject criteria of studies included participants who were in generally good health, liked the study foods, had no food allergies or intolerances, were not dieting or reported disordered eating or restrained eating, ate regular meals, were non-smokers, were not pregnant or breastfeeding, were not taking medications that affected appetite, and were not athletes in training.

#### Intervention/exposure and comparator

Most articles tested the effects of portion size on energy intake by examining intake at a single meal or snack. Thirteen articles tested the effects of varying the portion size of a single food on energy intake, examining the following types of foods: sandwiches,^36^ macaroni and cheese,^37,39,41,42^ pasta dishes,^29,38,68^ chili,^40^ popcorn,^30^ cookies,^67^ and ice cream.^66^ Eight articles tested the effects of varying the portion sizes of all foods served at the meal.^31,43–47,69^ Some of these articles focused solely on testing the effects of portion size, while some examined whether other factors moderate the portion size effect, such as engagement in activities while eating (reading a book, watching TV),^42,67^ self-serving food,^41^ labeling foods,^68^ or eating in a laboratory or a more naturalistic setting.^30^ Fourteen studies tested how varying the portion size of a test food effects other foods at the meal.^29,32,39,53,56,57,59,62,70^ ^34,61^

Fewer articles measured effects beyond a single meal. There were 5 articles that measured the effects of varying portion size on energy intake over the course of 1 day.^21,35,63,64^ Five articles were longer in duration and varied portion sizes of all foods over multiple days. These longer duration articles included an 8 week study in which the portions of foods at lunch were changed,^48^ as well as studies that changed the portion sizes of all meals and snacks served over 2,^49,50^ 4,^51^ and 11 days.^52^ There was 1 behavioral weight loss intervention that tested a portion control utensil set versus a portion control crockery set with participants using both sets of portion control tools for 4 weeks each.^65^

Finally, 6 interventions tested the combined effects of varying portion size and energy density of a single food or beverage.^33,54,55,58,63^

#### Outcome

The main outcome of interest was energy intake. Most articles assessed energy intake by weighing food before and after meals. For those that did not, there were two articles in a restaurant/cafeteria setting which weighed plate waste after the meal and subtracted the amount from the average serving weight. Calories were derived from recipes provided by the restaurant manager or chef. One article provided participants with boxed lunches for 4 weeks and used 2, 24-hour dietary recalls during each 4-week period in addition to participant self-report on consumption of boxed lunches. One article collected diet diaries to account for the remainder of the day’s intake in addition to measuring weighed food intake before and after the test meal. For interventions testing single foods, the outcome was energy intake of the test food.^29,30,36–42,66–68^ Interventions that varied the portion sizes of all foods at the meal reported total energy intake of the meal, with most also reporting energy intake of individual meal components.^31,43–47,69^ Interventions that measured the effects of portion size manipulations on other foods at the meal provided energy intakes for the test food, other foods served at the meal, and total meal energy intake.^29,32–34,39,53–63,70^ For longer term interventions, energy intakes were provided for the test food, total meal, and total daily energy intake^48–52^ with some providing effects on individual food components.^21,35,63,64^ Finally, the behavioral weight loss intervention measured daily energy intake via 3-day food diaries.^65^ See Table 18 for detailed energy intake assessment methods per article.

### Synthesis of the evidence

There were 13 articles that tested the effects of varying the portion size of a single food.^29,30,34,36–42,66–68^ The results from all studies indicate that as the portion size of the test food is increased, energy intake of the test food increases. In addition, among studies that tested a single food served as part of a meal, total energy intake at the meal also increased. There was 1 article where differences were found between men and women regarding ice cream intake served after a standard meal. The male participants increased energy intake of the ice cream, while there was no statistically significant increase in energy intake from the women, however, the direction of effect indicated increased energy intake.^66^

Among articles that varied the portion size of all foods at a meal,^31,43–47,69^ all showed that increasing portion sizes increased total energy intake at the meal, and 7 of the 8 articles reported outcomes for the individual foods served, and found portion size effects for the individual foods. Five of the articles tested the effects of portion size under different conditions and found that the effect persisted regardless of whether food was served or self-served, and with increased variety, but 2 articles reported no effect of varying portion size for certain foods served under certain conditions. One article found no effect of portion size on energy for the chicken and pasta meal components when participants were provided with a doggy bag, though there was a portion size effect for broccoli, garlic bread, and grapes.^45^ Notably, there was portion size effects for the chicken and pasta in the condition where a doggy bag was not offered.^45^ And in the other article, there was portion size effects for chicken, pasta, broccoli, salad, and garlic bread, but no effect on the grapes and chocolate chip cookies served at the meal.^46^ This article also found that among participants who had received training and education on the use of portion size as a strategy to moderate intake, participants were more likely to consume larger portions of lower energy dense foods.^46^

There was also a group of 11 articles comprising 14 interventions^29,32,34,53,56,57,59–62,70^ that tested the effects of increasing the portion size of one food served at the meal, reporting the effects on that test food, on other foods served at the meal, and on total energy intake at the meal. An additional 5 interventions within 4 studies tested effects over the course of a whole day.^21,35,63,64^ In nearly all studies, increasing the portion size of the test food increased energy intake from the test food. However, in one study, intake of the test food was compulsory,^61^ and in another study, there was no effect of portion size on intake of the test food.^60^ Effects on other foods served with the test food were more variable. The majority of studies showed that increasing the portion size, and intake, of a test food, did not have an effect on consumption of other foods served at the meal.^32,35,53,56,61–64^ In a few studies, increasing the portion size of a test food decreased intake of 1 or more other foods served at the meal.^21,32,35,57,59,64^ Only one article showed that increasing the portion size of an entrée increased the intake of other foods served (a tomato with pesto and a roll).^70^ Of the 13 studies that reported total energy intake at the meal,^29,32,34,35,53,56,57,59–63,70^ 10 showed that increasing the portion size of 1 food at the meal led to an increase in total energy intake at that meal.^29,34,35,56,57,59,62,63,70^ The remaining studies either did not report effects^32,53^ or showed no effect.^60,61^ All 5 studies that examined a full day of intake reported increased total daily energy intake.^21,29,35,63^ This suggests that the increased intake from the test food is not compensated for, either partially or fully, by reduced intake of other foods at the meal.

There were 5 articles^48–52^ that changed the portion size of all foods over multiple days. All showed increases in daily energy, energy intake at individual meals, and, when reported, of individual meal components. One article found differential effects of portion size depending on type of food group.^52^ There was a portion size effect for entrées, starches, desserts, yogurts, fruit with a meal, and snack foods, but no effect on fruit served as a snack or vegetables.

#### Portion size and energy density

Five articles were designed to test the independent and combined effects of portion size and energy density and can be found within Table 18.^33,54,55,58,63^ All 5 articles found the effects of portion size and energy density on energy intake to be both independent and additive, particularly when higher energy dense foods were served. One article with 2 experiments tested portion size and energy density on the vegetable side dish (broccoli) either adding the additional portion sizes and energy densities to the meal or simultaneously decreasing the portion size of the other meal components.^33^ These experiments reported increased energy intakes of the vegetable (manipulated test food) with 1 experiment reporting statistically significant increases in total meal energy intake with the other experiment showing a direction of effect for increased total meal energy intake but overall, no statistically significant effect.^33^ Two articles offered salads as a compulsory first course in conditions that were systematically varied by portion size and energy density; a no salad control condition was also included. In the first article, compared with a no salad control, consuming low energy dense salads reduced meal energy intake and consuming high energy dense salads increased meal energy intake.^54^ This article also found decreased entrée intake with the low energy dense salads compared to the high energy dense salads.^54^ In the other article, a pasta entrée was increased in portion size and energy density with either a salad first course or no salad first course. This article found increased energy intakes of the pasta entrée and meal energy intake with increased pasta portion size and energy density, while consuming a salad decreased energy intake of the pasta but did not affect total energy intake at meal.^55^ Another article tested portion size and energy density of different beverages.^58^ This article reported increased intakes of the beverages with no effect on other foods served. For total meal energy intake, energy intake increased with the high energy dense/caloric beverages but had no effect for total meal energy intake when the low energy dense/non-caloric beverages were consumed.^58^ Finally, one article increased the portion size and energy density of a baked pasta dish which resulted in increased energy intakes of the baked pasta and total meal energy intake but had no effect on the other food served.^63^ Taken together, these articles consistently show that serving high energy dense versions of food increases energy intake, serving larger portions of a food increases energy intake, and together they lead to even greater increases in energy intake.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed 2 conclusion statements to answer the question, “What is the relationship between portion size and energy intake?” based on their review of the body evidence on portion sizes served to adults and older adults (Table 8 and Table 9).

Table 8 Conclusion statement and grade for portion size and energy intake in adults and older adults

Conclusion Statement | Serving larger portions of foods increases food and energy intake in adults and older adults. This conclusion statement is based on evidence graded as strong.
Grade | Strong
Body of Evidence | Forty-three articles comprising 51 interventions: 39 RCT-Crossover; 9 RCT-Parallel; 3 NRCT
Consistency | Few concerns with consistency. Strengths demonstrated by consistent direction and magnitude of effects with similar study designs and methods used.
Precision | Few concerns with precision. Strengths demonstrated by studies with sufficient power.
Risk of Bias | Some concerns with risk of bias due to a lack of information about randomization methods and the potential for selective reporting of results.
Directness | Few concerns with directness. The studies were directly designed to examine the effects of portion size and energy intake.
Generalizability | Some concerns with generalizability due to a lack of diversity for study participants with regards to race and ethnicity and socioeconomic position.

Table 9 Conclusion statement and grade for portion size and energy intake in adults and older adults

Conclusion Statement | Portion size and energy density are independent and additive in their effects on energy intake in adults and older adults. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | Five articles comprising 6 interventions directly tested portion size and energy density: 6 RCT-Crossover; - An additional 6 articles demonstrated effects of portion size on low energy dense foods although it was not the primary purpose of the articles: 5 RCT-Crossover; 1 RCT-Parallel
Consistency | Few concerns with consistency. Strengths demonstrated by consistent direction and magnitude of effects with similar study designs and methods used.
Precision | Few concerns with precision. Strengths demonstrated by studies with sufficient power.
Risk of Bias | Some concerns with risk of bias due to a lack of information about randomization methods and the potential for selective reporting of results.
Directness | Few concerns with directness. The studies in this subset were directly designed to examine the effects of portion size and energy density on energy intake.
Generalizability | Several concerns with generalizability due to a lack of diversity for study participants with regards to race and ethnicity and socioeconomic position.

#### Assessment of the evidence

The body of evidence included 43 articles comprising 51 interventions. Of these, 39 were crossover randomized controlled trials, 9 were parallel arm randomized controlled trials, and 3 were non-randomized controlled trials. Most articles reported effects of the manipulated foods as well as other foods served, total meal, and though fewer, some did report on daily energy intakes. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, there was a small number of articles with null findings, which indicates that publication bias, though possibly present, was likely not a major concern within this body of evidence.

##### Consistency

The body of evidence included strong study designs with consistent findings in direction and effect. There were few articles with overall null results. Given most reported effects on the manipulated food, other foods, and/or total energy intake, results were comparable in direction and effect.

##### Precision

There were few concerns with precision. There were adequate number of articles with sample sizes ranging from N=13 to N=154 with a few larger (up to N=603) articles conducted in worksites/college cafeterias. While there were fewer articles examining portion size and energy density, most reported power calculations and were adequately powered.

##### Risk of bias

There were some concerns for risks of bias for most articles surrounding lack of information provided about randomization and concealment methods, lack of details on attrition/those excluded from analysis and having no pre-registered protocol or data analysis plans increasing the potential for selective reporting of results. Despite these risks of bias, there was little indication that randomization was not effective or that selective reporting occurred. A few articles had higher risks of bias which included concerns for self-reporting, not accounting for the rest of the diet, no power calculation, not accounting for all key confounders, and concerns with outcome assessment methods (Table 19 and Table 20).

##### Directness

Nearly all articles were directly designed to test the effects of portion size on energy intake. Some tested other factors that impact the relationship (food characteristics including energy density, protein, or variety), setting or environment (naturalistic vs. laboratory, TV viewing, reading a book, conducting a body scan, blind folding, bowl size, contextual information, self-serving, or provided with a doggy bag) and socioeconomic position. There were fewer articles that directly tested the relationship between portion size and energy density, however, in those that did most indicated that serving larger portion sizes increases energy intake, serving high energy dense food increases energy intake, and together, they substantially increase energy intake.

##### Generalizability

There were some concerns with generalizability due to a lack of diversity for study participants with regards to race and ethnicity and socioeconomic position. Most articles were conducted in predominately White, non-Hispanic populations of middle to high socioeconomic position. However, regardless of where the study was conducted, and who the participants were, results were consistent with participant characteristics reflective of the U.S. population.

## Pre-portioned foods in adults and older adults

### Description of the evidence

Eight articles met inclusion criteria to examine the relationship between the consumption of pre-portioned foods by adults and older adults and energy intake.^71–78^ Of the 8 articles, 6 were parallel arm randomized controlled trials^71–73,75,77,78^ and 2 were crossover randomized controlled trials.^74,76^ This body of evidence is summarized in Table 23.

#### Population

Most articles were conducted in the U.S.,^71–77^ while 1 was conducted in The Netherlands.^78^ Sample sizes ranged from N=20 to N=229. One article enrolled only women^75^ while 7 enrolled both men and women, though most participants overall were women. Participants ranged in age from 20-50 years, with most participants having a mean age less than 25 years. Participants were generally free from disease, not dieting to gain or lose weight, not exhibiting disordered eating symptoms or behaviors, and not taking medications known to impact appetite. Body mass index ranged from approximately 22 to 34 kg/m^2^. In the 5 articles that described participant race and/or ethnicity, participants were predominately in White, non-Hispanic populations.^71–73,75,77^ In the 4 articles that provided information about socioeconomic position, participants reported having earned a college degree, higher incomes (>$40,000), and were married.^71–73,75^

#### Intervention/exposure and Comparator

The articles in this body of evidence conducted interventions to determine the effects of serving pre-portioned foods, though the articles varied in terms of the methods used to pre-portion foods, whether they tested meals or snacks, and the duration of the intervention. One study compared the effects of pre-portioned box lunches that differed in portion size (calorie amounts) to a habitual lunch over a 6-month period.^71^ Another study compared the effects of serving the same amount of pretzels in single serve packages or standard multi-serving packages over 4 days.^72^ One study compared the effects of providing breakfast foods as single-serve items to the same breakfast foods provided in standard, non-portioned amounts over 8 weeks.^73^ Another study tested the effects of serving the same amount of snacks in smaller compared to larger packages over 3 days.^74^ As part of a 12 month behavioral weight loss intervention, one study compared the effects of pre-portioned foods (given as pre-paid vouchers for single-serving main dishes) to a portion selection group (a group instructed to choose food portions based on energy density), or a standard dietary advice group.^75^ Another study tested the effects of providing breakfast, lunch, and dinner foods served in standard unit sizes compared to serving the same foods cut into smaller pieces, or units.^76^ This article also tested the effects of energy density, serving each unit size condition in lower and higher energy density versions. One study compared the effects of providing snacks that varied both in package size and number of packages over 3 days.^77^ Finally, one study compared the effects of serving the same amount of chocolate as either large bars or smaller bars at a single snack session.^78^ This article also tested the effects of wrappers, serving the bars wrapped and unwrapped.

#### Outcome

All articles measured energy intake as an outcome of interest (Table 23). Six of 8 articles assessed energy intake via weighed food intake,^72–74,76–78^ and 2 measured energy intake by conducting 3, 24-hour dietary recalls.^71,75^ In addition, 3 of the articles were weight loss interventions, in which energy intake was also measured.^71,73,75^

### Synthesis of the evidence

Most articles reported consistent findings, showing that energy intake was higher when participants were served larger compared to smaller pre-portioned foods. Four articles reported statistically significant differences between groups. One study found energy intake of the lunch meal to be significantly higher in the 1600 calorie boxed lunch group compared to all other groups. Lunch energy intake was significantly higher for the 800-calorie boxed lunch group when compared to the 400-calorie boxed lunch group. While the 1600 calorie boxed lunch group energy intake of the meal was higher compared to the 800- and 400-calorie groups, total daily energy intake was not different compared to the control group consuming a habitual lunch. Total daily energy intake was not different between the 800- and 400-calorie groups either.^71^ However, total daily energy intake was significantly higher in the control group compared to the 400-calorie lunch box group.^71^ Another study reported total daily energy intake was significantly higher in participants served the standard, non-pre-portioned breakfast compared to the single-serve pre-portioned breakfast.^73^ This effect did differ by type of food with energy intakes from cereal and applesauce higher in the non-pre-portioned breakfast compared to the pre-portioned breakfast. There were no significant differences in energy intake from peaches and cheese between groups.^73^ In another study, there was increased energy intakes when the larger compared to smaller packaged snacks were served^74^ and in another, increased energy intakes with the larger chocolate bars compared to smaller units of chocolate bars.^78^

Three articles did not find statistically significant increases in energy intakes, but the direction of effect was similar. One study found no statistically significant differences in snack energy intake in participants who were served a standard versus single-serving snack package, though energy intake was higher when the standard package size was served.^72^ In addition, participants with overweight or obesity in this study consumed significantly more calories from the standard packages compared to those with normal weight, but no difference was found for single serving packages.^72^ Another study reported a main effect of package size, as energy intake was significantly higher in the large compared to the small package groups.^77^ However, there were no differences in energy intake from snack foods between the large and small unit groups, and the interaction between unit size and package size was not significant. One study found no significant differences in energy intake between the pre-portioned foods group, portion selection group, and standard dietary advice group.^75^ However, within group analyses showed that all groups decreased energy intake significantly from baseline, suggesting that pre-portioned foods did effectively decrease energy intakes, but was no better than the other strategies tested in the intervention.^75^

Finally, one study tested the effects of serving an omelet, wraps, and pizzas in standard sizes compared to cutting them into smaller pieces, found no differences in energy intake.^76^ This study also tested the effects of energy density, and reported that increasing energy density significantly increased energy intake.^76^

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between portion size and energy intake?” based on their review of the body evidence on pre-portioned food served to adults and older adults (Table 10).

Table 10 Conclusion statement and grade for pre-portioned food and energy intake in adults and older adults

Conclusion Statement | Serving foods as smaller pre-portioned amounts decreases energy intake in adults and older adults. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | Eight articles: 6 RCT-Parallel; 2 RCT-Crossover
Consistency | Some concerns with consistency. The direction of results consistently showed that energy intake was lower when food was served in smaller, pre-portioned amounts, though effect size varied.
Precision | Some concerns with precision due to the small size of study groups and variance in effect estimates.
Risk of bias | Some concerns with risks of bias due to a lack of information about randomization methods and the potential for selective reporting of results.
Directness | Few concerns with directness. The studies were directly designed to examine the effects of pre-portioned foods on energy intake.
Generalizability | Several concerns with generalizability due to a lack of diversity for study participants with regards to race and ethnicity and socioeconomic position.

#### Assessment of the evidence

The body of evidence underlying these conclusion statements comes from 8 randomized controlled trials, including 6 parallel arm randomized controlled trials and 2 crossover randomized controlled trials. The strength of the evidence was graded based on an assessment of 5 grading elements, as described below. Publication bias was also considered, and there are some concerns with publication bias for this body of evidence. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, several of the included articles did report null findings.

##### Consistency

The body of evidence was generally consistent with respect to the direction of effect of the findings, though there was some variability in terms of the magnitude of effect reported. The direction of results consistently showed that energy intake was lower when food was served in smaller, pre-portioned amounts. However, given that studies tested different types of foods over different durations, the magnitude of the change of energy intake varied across studies.

##### Precision

The body of evidence demonstrated precision given the adequate number of sufficiently powered studies. However, there were some concerns with precision due to the generally small size of study groups and variance in effect estimates.

##### Risk of bias

Across the body of evidence, there were some concerns with risks of bias. This was primarily due to a lack of information about randomization methods and the potential for selective reporting of results, due to a lack of pre-registered protocols or data analysis plans. However, despite these concerns, there was little indication that randomization was not effective or that selective reporting of results occurred (Table 24).

##### Directness

There were few concerns with directness in this body of evidence. Articles were directly designed to examine the effects of pre-portioned foods on energy intake in adults and older adults.

##### Generalizability

There were several concerns with generalizability in this body of evidence. These concerns are primarily due to a lack of diversity for study participants with regards to race and ethnicity and socioeconomic position. Several articles did not describe participant characteristics for these variables, and among those that did, participants were majority non-Hispanic White, and of higher socioeconomic position due to education and income.

## Portion size in individuals during pregnancy

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between portion size and energy intake?” based on their review of the body evidence on portion sizes served to individuals during pregnancy (Table 11). There were no articles in the body of evidence, so a conclusion statement could be not drawn. Due to the lack of evidence identified, it is difficult to evaluate publication bias. While the literature search was comprehensive, a search of the gray literature was not conducted, and therefore there are some concerns that publication bias contributed to the lack of articles available for inclusion in this body of evidence.

Table 11 Conclusion statement and grade for portion size and energy intake in individuals during pregnancy

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between portion size and energy intake during pregnancy because there is no evidence available.
Grade | Grade not assignable
Body of Evidence | 0 articles
Rationale | There is not enough evidence available to answer this question.

## Pre-portioned foods in individuals during pregnancy

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between portion size and energy intake?” based on their review of the body evidence on pre-portioned foods served to individuals during pregnancy (Table 12). There were no articles in the body of evidence, so a conclusion statement could be not drawn. Due to the lack of evidence identified, it is difficult to evaluate publication bias. While the literature search was comprehensive, a search of the gray literature was not conducted, and therefore there are some concerns that publication bias contributed to the lack of articles available for inclusion in this body of evidence.

Table 12 Conclusion statement and grade for pre-portioned foods and energy intake in individuals during pregnancy

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between pre-portioned foods and energy intake during pregnancy because there is no evidence available.
Grade | Grade not assignable
Body of Evidence | 0 articles
Rationale | There is not enough evidence available to answer this question.

## Portion size in individuals during postpartum

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between portion size and energy intake?” based on their review of the body evidence on portion sizes served to individuals during postpartum (Table 13). There were no articles in the body of evidence, so a conclusion statement could be not drawn. Due to the lack of evidence identified, it is difficult to evaluate publication bias. While the literature search was comprehensive, a search of the gray literature was not conducted, and therefore there are some concerns that publication bias contributed to the lack of articles available for inclusion in this body of evidence.

Table 13 Conclusion statement and grade for portion size and energy intake in individuals during postpartum

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between portion size and energy intake during postpartum because there is no evidence available.
Grade | Grade not assignable
Body of Evidence | 0 articles
Rationale | There is not enough evidence available to answer this question.

## Pre-portioned foods in individuals during postpartum

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between portion size and energy intake?” based on their review of the body evidence on pre-portioned foods served to individuals during postpartum (Table 14). There were no articles in the body of evidence, so a conclusion statement could be not drawn. Due to the lack of evidence identified, it is difficult to evaluate publication bias. While the literature search was comprehensive, a search of the gray literature was not conducted, and therefore there are some concerns that publication bias contributed to the lack of articles available for inclusion in this body of evidence.

Table 14 Conclusion statement and grade for pre-portioned foods and energy intake in individuals during postpartum

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between pre-portioned foods and energy intake during postpartum because there is no evidence available.
Grade | Grade not assignable
Body of Evidence | 0 articles
Rationale | There is not enough evidence available to answer this question.