# Plain language summary

### What is the question?

The question is: What is the relationship between portion size and energy intake? The populations of interest for this question include young children, children, adolescents, adults, older adults, and individuals during pregnancy and postpartum.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team.

### What is the answer to the question?

- Serving larger portions of energy dense foods increases energy intake in children. This conclusion statement is based on evidence graded as strong.
- Serving larger portions of vegetables and fruits increases intake of those foods without increasing energy intake in children. This conclusion statement is based on evidence graded as moderate.
- A conclusion statement cannot be drawn about the relationship between portion size and energy intake in young children and adolescents because there is no evidence available.
- A conclusion statement cannot be drawn about the relationship between pre-portioned foods by young children, children, and adolescents and energy intake because there is not enough evidence available.
- Serving larger portions of foods increases food and energy intake in adults and older adults. This conclusion statement is based on evidence graded as strong.
- Portion size and energy density are independent and additive in their effects on energy intake in adults and older adults. This conclusion statement is based on evidence graded as moderate.
- Serving foods as smaller pre-portioned amounts decreases energy intake in adults and older adults. This conclusion statement is based on evidence graded as moderate.
- A conclusion statement cannot be drawn about the relationship between portion size and energy intake during pregnancy because there is no evidence available.
- A conclusion statement cannot be drawn about the relationship between pre-portioned foods and energy intake during pregnancy because there is no evidence available.
- A conclusion statement cannot be drawn about the relationship between portion size and energy intake during postpartum because there is no evidence available.
- A conclusion statement cannot be drawn about the relationship between pre-portioned foods and energy intake during postpartum because there is no evidence available.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 2000 and January 2024.