# Appendix 3 Excluded articles

The following table lists the articles excluded after full-text screening for this systematic review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 6 Articles excluded after full-text screening

| Citation | Exclusion Reason
1 | Factors influencing restaurant portion sizes and subsequent energy intake. Nat Clinic Pract Endocrinol Metab. 2007.3:792. doi:10.1038/ncpendmet0656 | Publication status
2 | High-tech approach to portion control aids kids. Care Management. 2010.16:27-27. | Study design
3 | Portion markers aid weight loss. Nursing Times. 2007.103:7-7 | Study design
4 | Portion-control plate is an effective tool to induce weight loss. Nat Clin Pract Endocrinol Metab. 2007. 3:675-676. doi:10.1038/ncpendmet0604 | Publication status; Study design
5 | Abeywickrema, S.,Peng, M. The Role of Tableware Size in Healthy Eating-Effects on Downstream Food Intake. Foods. 2023;12(6):1230. doi:10.3390/foods12061230 | Intervention/exposure
6 | Adachi, C.,Yamanaka-Okumura, H.,Zhou, B.,Kawakami, Y.,Katayama, T.,Takeda, E. PP188-MON EFFECT OF DIETARY ENERGY DENSITY ON FULLNESS AND SATISFACTION IS MODULATED BY HABITUAL DAILY VEGETABLE INTAKE. Clin Nutr Suppl. 2012. 7:212-213. doi:10.1016/S1744-1161(12)70527-6 | Publication status
7 | Afaghi, A.,Ziaee, A.,Kiaee, S. M.,Hosseini, N. Glycemic index and glycemic loads of variety of fruits: Clinical implementation of fruits’ serving size in low glycemic load diet. Curr Top Nutraceutical Res. 2009. 7:157-160. | Intervention/exposure
8 | Alencar MK, Beam JR, McCormick JJ, et al. Increased meal frequency attenuates fat-free mass losses and some markers of health status with a portion-controlled weight loss diet. Nutr Res. 2015;35(5):375-383. doi:10.1016/j.nutres.2015.03.003 | Duration; Intervention/exposure
9 | Ali HI, Platat C, El Mesmoudi N, El Sadig M, Tewfik I. Evaluation of a photographic food atlas as a tool for quantifying food portion size in the United Arab Emirates. PLoS One. 2018;13(4):e0196389. doi:10.1371/journal.pone.0196389 | Outcome; Study design
10 | Alkerwi, A.,Crichton, G. E.,Hébert, J. R. Consumption of ready-made meals and increased risk of obesity: findings from the Observation of Cardiovascular Risk Factors in Luxembourg (ORISCAV-LUX) study. Br J Nutr. 2015.113 (2):270-7. doi:10.1017/s0007114514003468 | Study design
11 | Almiron-Roig E, Domínguez A, Vaughan D, Solis-Trapala I, Jebb SA. Acceptability and potential effectiveness of commercial portion control tools amongst people with obesity. Br J Nutr. 2016;116(11):1974-1983. doi:10.1017/S0007114516004104 | Outcome
12 | Alper, B. S. Evidence-based medicine. Portion-control plate promotes modest weight loss. Clinical Advisor. 2008. 11:131-131. | Publication status; Study design
13 | Ayaz A, Akyol A, Cetin C, Besler HT. Effect of plate size on meal energy intake in normal weight women. Nutr Res Pract. 2016;10(5):524-529. doi:10.4162/nrp.2016.10.5.524 | Intervention/exposure
14 | Bailey-Davis L, Poulsen MN, Hirsch AG, Pollak J, Glass TA, Schwartz BS. Home Food Rules in Relation to Youth Eating Behaviors, Body Mass Index, Waist Circumference, and Percent Body Fat. J Adolesc Health. 2017;60(3):270-276. doi:10.1016/j.jadohealth.2016.09.020 | Intervention/exposure; Study design
15 | Balbi, A. Portion-Controlled Diets Are Better for Weight Loss Than Seif-Selected Diets. Consultant (00107069). 2016.56:580-580. | Study design
16 | Banna JC, Panizza CE, Boushey CJ, Delp EJ, Lim E. Association between Cognitive Restraint, Uncontrolled Eating, Emotional Eating and BMI and the Amount of Food Wasted in Early Adolescent Girls. Nutrients. 2018;10(9):1279. Published 2018 Sep 10. doi:10.3390/nu10091279 | Study design
17 | Barnard ND, Levin SM, Gloede L, Flores R. Turning the Waiting Room into a Classroom: Weekly Classes Using a Vegan or a Portion-Controlled Eating Plan Improve Diabetes Control in a Randomized Translational Study. J Acad Nutr Diet. 2018. 118(6):1072-1079. doi:10.1016/j.jand.2017.11.017 | Health status; Intervention/exposure
18 | Barrientos-Gutiérrez T, Illescas-Zárte D, Batis C, et al. Association between consumption of nonessential energy-dense food and body mass index among Mexican school-aged children: A prospective cohort study. Preprint. Res Sq. 2023;rs.3.rs-2833950. doi:10.21203/rs.3.rs-2833950/v1 | Intervention/exposure
19 | Barton KL, Wrieden WL, Sherriff A, Armstrong J, Anderson AS. Energy density of the Scottish diet estimated from food purchase data: relationship with socio-economic position and dietary targets. Br J Nutr. 2014;112(1):80-88. doi:10.1017/S0007114514000294 | Intervention/exposure
20 | Bates KJ, Byker Shanks C. Placement of a take-out container during meal influences energy intake. Eat Behav. 2015;19:181-183. doi:10.1016/j.eatbeh.2015.09.004 | Intervention/exposure
21 | Batra P, Das SK, Salinardi T, et al. Relationship of cravings with weight loss and hunger. Results from a 6 month worksite weight loss intervention. Appetite. 2013;69:1-7. doi:10.1016/j.appet.2013.05.002 | Outcome; Intervention/exposure
22 | Bell EA, Rolls BJ. Energy density of foods affects energy intake across multiple levels of fat content in lean and obese women. Am J Clin Nutr. 2001;73(6):1010-1018. doi:10.1093/ajcn/73.6.1010 | Intervention/exposure
23 | Berg C, Lappas G, Wolk A, et al. Eating patterns and portion size associated with obesity in a Swedish population. Appetite. 2009;52(1):21-26. doi:10.1016/j.appet.2008.07.008 | Study design
24 | Berrut G, Favreau AM, Dizo E, et al. Estimation of calorie and protein intake in aged patients: validation of a method based on meal portions consumed. J Gerontol A Biol Sci Med Sci. 2002;57(1):M52-M56. doi:10.1093/gerona/57.1.m52 | Intervention/exposure; Study design
25 | Best M, Papies EK. Lower socioeconomic status is associated with higher intended consumption from oversized portions of unhealthy food. Appetite. 2019;140:255-268. doi:10.1016/j.appet.2019.05.009 | Outcome
26 | Bish B, Regis K, Gottesman MM. Educating parents about portion sizes for preschoolers. J Pediatr Health Care. 2005;19(1):54-59. doi:10.1016/j.pedhc.2004.12.001 | Study design
27 | Blatt AD, Roe LS, Rolls BJ. Hidden vegetables: an effective strategy to reduce energy intake and increase vegetable intake in adults. Am J Clin Nutr. 2011;93(4):756-763. doi:10.3945/ajcn.110.009332 | Intervention/exposure
28 | Blatt AD, Williams RA, Roe LS, Rolls BJ. Effects of energy content and energy density of pre-portioned entrées on energy intake. Obesity (Silver Spring). 2012;20(10):2010-2018. doi:10.1038/oby.2011.391 | Intervention/exposure
29 | Bohnert AM, Randall ET, Tharp S, Germann J. The development and evaluation of a portion plate for youth: a pilot study. J Nutr Educ Behav. 2011;43(4):268-273. doi:10.1016/j.jneb.2010.07.007 | Comparator; Intervention/exposure
30 | Brunstrom JM, Collingwood J, Rogers PJ. Perceived volume, expected satiation, and the energy content of self-selected meals. Appetite. 2010;55(1):25-29. doi:10.1016/j.appet.2010.03.005 | Outcome; Intervention/exposure
31 | Brunstrom JM, Jarvstad A, Griggs RL, et al. Large Portions Encourage the Selection of Palatable Rather Than Filling Foods. J Nutr. 2016;146(10):2117-2123. doi:10.3945/jn.116.235184 | Outcome
32 | Brunstrom JM, Rogers PJ, Pothos EM, Calitri R, Tapper K. Estimating everyday portion size using a ‘method of constant stimuli’: in a student sample, portion size is predicted by gender, dietary behaviour, and hunger, but not BMI. Appetite. 2008;51(2):296-301. doi:10.1016/j.appet.2008.03.005 | Outcome
33 | Brunstrom JM. The control of meal size in human subjects: a role for expected satiety, expected satiation and premeal planning. Proc Nutr Soc. 2011;70(2):155-161. doi:10.1017/S002966511000491X | Publication status; Study design
34 | Buckland NJ, Camidge D, Croden F, et al. A Low Energy-Dense Diet in the Context of a Weight-Management Program Affects Appetite Control in Overweight and Obese Women. J Nutr. 2018;148(5):798-806. doi:10.1093/jn/nxy041 | Intervention/exposure
35 | Burger KS, Kern M, Coleman KJ. Characteristics of self-selected portion size in young adults. J Am Diet Assoc. 2007;107(4):611-618. doi:10.1016/j.jada.2007.01.006 | Outcome; Intervention/exposure
36 | Cecil JE, Palmer CN, Wrieden W, et al. Energy intakes of children after preloads: adjustment, not compensation. Am J Clin Nutr. 2005;82(2):302-308. doi:10.1093/ajcn.82.2.302 | Comparator; Intervention/exposure
37 | Cheon BK, Sim AY, Lee L, Forde CG. Avoiding hunger or attaining fullness? Implicit goals of satiety guide portion selection and food intake patterns. Appetite. 2019;138:10-16. doi:10.1016/j.appet.2019.03.003 | Comparator; Intervention/exposure
38 | Chou T, Hoover AW, Goldstein SP, et al. An explanation for the accuracy of sensor-based measures of energy intake: Amount of food consumed matters more than dietary composition. Appetite. 2024;194:107176. doi:10.1016/j.appet.2023.107176 | Intervention/exposure
39 | Coleman CD, Kiel JR, Mitola AH, Arterburn LM. Comparative effectiveness of a portion-controlled meal replacement program for weight loss in adults with and without diabetes/high blood sugar. Nutr Diabetes. 2017;7(7):e284. doi:10.1038/nutd.2017.32 | Intervention/exposure; Study design
40 | Collins CE, Morgan PJ, Warren JM, Lubans DR, Callister R. Men participating in a weight-loss intervention are able to implement key dietary messages, but not those relating to vegetables or alcohol: the Self-Help, Exercise and Diet using Internet Technology (SHED-IT) study. Public Health Nutr. 2011;14(1):168-175. doi:10.1017/S1368980010001916 | Intervention/exposure
41 | Cowbrough K. Healthier choices and portions for older children. J Fam Health. 2016;26(2):29-32. | Study design
42 | Cowbrough K. Part one: Portion control during infancy and toddler years. J Fam Health. 2015;25(4):16-19. | Study design
43 | Cox JS, Hinton EC, Sauchelli S, Hamilton-Shield JP, Lawrence NS, Brunstrom JM. When do children learn how to select a portion size? Appetite. 2021;164:105247. doi:10.1016/j.appet.2021.105247 | Comparator; Intervention/exposure; Study design
44 | Cullen KW, Thompson DI. Texas school food policy changes related to middle school a la carte/snack bar foods: potential savings in kilocalories. J Am Diet Assoc. 2005. 105(12):1952-4. doi:10.1016/j.jada.2005.09.008 | Outcome; Study design
45 | Cunningham E. What impact does plate size have on portion control? J Am Diet Assoc. 2011;111(9):1438. doi:10.1016/j.jada.2011.07.027 | Study design
46 | Cunningham PM, Roe LS, Keller KL, Hendriks-Hartensveld AEM, Rolls BJ. Eating rate and bite size were related to food intake across meals varying in portion size: A randomized crossover trial in adults. Appetite. 2023;180:106330. doi:10.1016/j.appet.2022.106330 | Duplicate
47 | de Castro JM. Stomach filling may mediate the influence of dietary energy density on the food intake of free-living humans. Physiol Behav. 2005;86(1-2):32-45. doi:10.1016/j.physbeh.2005.06.032 | Comparator; Intervention/exposure; Study design
48 | De Ridder D, De Vet E, Stok M, Adriaanse M, De Wit, J. Obesity, overconsumption and self-regulation failure: the unsung role of eating appropriateness standards. Health Psychol Rev. 2013.7:146-165. doi:10.1080/17437199.2012.706987 | Study design
49 | Diktas HE, Roe LS, Keller KL, Rolls BJ. The effects of snack foods of different energy density on self-served portions and consumption in preschool children. Appetite. 2023;185:106527. doi:10.1016/j.appet.2023.106527 | Comparator; Intervention/exposure
50 | DiSantis KI, Birch LL, Davey A, et al. Plate size and children’s appetite: effects of larger dishware on self-served portions and intake. Pediatrics. 2013;131(5):e1451-e1458. doi:10.1542/peds.2012-2330 | Intervention/exposure
51 | Divert C, Laghmaoui R, Crema C, Issanchou S, Wymelbeke VV, Sulmont-Rossé C. Improving meal context in nursing homes. Impact of four strategies on food intake and meal pleasure. Appetite. 2015;84:139-147. doi:10.1016/j.appet.2014.09.027 | Comparator
52 | Doumit R, Long J, Kazandjian C, et al. Effects of Recording Food Intake Using Cell Phone Camera Pictures on Energy Intake and Food Choice. Worldviews Evid Based Nurs. 2016;13(3):216-223. doi:10.1111/wvn.12123 | Intervention/exposure
53 | Dubois L, Bédard B, Goulet D, Prud’homme D, Tremblay RE, Boivin M. Eating behaviors, dietary patterns and weight status in emerging adulthood and longitudinal associations with eating behaviors in early childhood. Int J Behav Nutr Phys Act. 2022;19(1):139. Published 2022 Nov 16. doi:10.1186/s12966-022-01376-z | Intervention/exposure
54 | Durão C, Severo M, Oliveira A, et al. Evaluating the effect of energy-dense foods consumption on preschool children’s body mass index: a prospective analysis from 2 to 4 years of age. Eur J Nutr. 2015;54(5):835-843. doi:10.1007/s00394-014-0762-4 | Intervention/exposure
55 | Ebbeling CB, Garcia-Lago E, Leidig MM, Seger-Shippee LG, Feldman HA, Ludwig DS. Altering portion sizes and eating rate to attenuate gorging during a fast food meal: effects on energy intake. Pediatrics. 2007;119(5):869-875. doi:10.1542/peds.2006-2923 | Intervention/exposure
56 | Edwards JS. Portion distortion: a food service viewpoint. J R Soc Promot Health. 2005;125(3):109-110. doi:10.1177/146642400512500311 | Study design
57 | Egnell M, Kesse-Guyot E, Galan P, et al. Impact of Front-of-Pack Nutrition Labels on Portion Size Selection: An Experimental Study in a French Cohort. Nutrients. 2018;10(9):1268. Published 2018 Sep 8. doi:10.3390/nu10091268 | Outcome; Intervention/exposure
58 | Ello-Martin JA, Roe LS, Ledikwe JH, Beach AM, Rolls BJ. Dietary energy density in the treatment of obesity: a year-long trial comparing 2 weight-loss diets. Am J Clin Nutr. 2007;85(6):1465-1477. doi:10.1093/ajcn/85.6.1465 | Intervention/exposure
59 | Embling R, Price MJ, Lee MD, Jones A, Wilkinson LL. Associations between dietary variety, portion size and body weight: prospective evidence from UK Biobank participants. Br J Nutr. 2023;130(7):1267-1277. doi:10.1017/S0007114523000156 | Intervention/exposure
60 | English LK, Fearnbach SN, Lasschuijt M, et al. Brain regions implicated in inhibitory control and appetite regulation are activated in response to food portion size and energy density in children. Int J Obes (Lond). 2016;40(10):1515-1522. doi:10.1038/ijo.2016.126 | Outcome
61 | English LK, Fearnbach SN, Wilson SJ, et al. Food portion size and energy density evoke different patterns of brain activation in children. Am J Clin Nutr. 2017;105(2):295-305. doi:10.3945/ajcn.116.136903 | Outcome
62 | Epstein LH, Fletcher KD, O’Neill J, Roemmich JN, Raynor H, Bouton ME. Food characteristics, long-term habituation and energy intake. Laboratory and field studies. Appetite. 2013;60(1):40-50. doi:10.1016/j.appet.2012.08.030 | Comparator; Intervention/exposure
63 | Eykelenboom M, Velema E, Eberson BPD, Scholten GC, Lushpa VK, Steenhuis IHM. Results of a randomized controlled trial evaluating the effect of increasing package size on usage volume of peanut butter in older adults. Appetite. 2018;130:184-189. doi:10.1016/j.appet.2018.08.008 | Outcome
64 | Faucher MA. Promotoras de salud and portion control: a community intervention aimed at weight loss in low-income Mexican-American women. J Midwifery Womens Health. 2008.53:482 | Publication status; Study design
65 | Faulkner GP, Pourshahidi LK, Wallace JM, Kerr MA, McCaffrey TA, Livingstone MB. Perceived ‘healthiness’ of foods can influence consumers’ estimations of energy density and appropriate portion size. Int J Obes (Lond). 2014;38(1):106-112. doi:10.1038/ijo.2013.69 | Duration; Outcome; Comparator; Study design
66 | Fazzino TL, Courville AB, Guo J, Hall KD. Ad libitum meal energy intake is positively influenced by energy density, eating rate and hyper-palatable food across four dietary patterns. Nat Food. 2023;4(2):144-147. doi:10.1038/s43016-022-00688-4 | Duration; Intervention/exposure
67 | Fazzino TL, Dorling JL, Apolzan JW, Martin CK. Meal composition during an ad libitum buffet meal and longitudinal predictions of weight and percent body fat change: The role of hyper-palatable, energy dense, and ultra-processed foods. Appetite. 2021;167:105592. doi:10.1016/j.appet.2021.105592 | Intervention/exposure
68 | Ferrar J, Griggs RL, Stuijfzand BG, Rogers PJ. Food portion size influences accompanying beverage selection in adults. Appetite. 2019;136:103-113. doi:10.1016/j.appet.2019.01.017 | Outcome; Intervention/exposure; Study design
69 | Ferriday D, Bosworth ML, Godinot N, et al. Variation in the Oral Processing of Everyday Meals Is Associated with Fullness and Meal Size; A Potential Nudge to Reduce Energy Intake?. Nutrients. 2016;8(5):315. Published 2016 May 21. doi:10.3390/nu8050315 | Intervention/exposure
70 | Ferriday D, Brunstrom JM. How does food-cue exposure lead to larger meal sizes?. Br J Nutr. 2008;100(6):1325-1332. doi:10.1017/S0007114508978296 | Comparator; Intervention/exposure
71 | Flieh SM, Miguel-Berges ML, Huybrechts I, et al. Associations between food portion sizes, insulin resistance, VO2 max and metabolic syndrome in European adolescents: The HELENA study. Nutr Metab Cardiovasc Dis. 2022;32(9):2061-2073. doi:10.1016/j.numecd.2022.05.017 | Study design
72 | Flynn AN, Rogers PJ, Brunstrom JM. Further evidence for sensitivity to energy density and a two-component model of meal size: Analysis of meal calorie intakes in Argentina and Malaysia. Physiol Behav. 2023;270:114314. doi:10.1016/j.physbeh.2023.114314 | Study design
73 | Flynn AN, Hall KD, Courville AB, Rogers PJ, Brunstrom JM. Time to revisit the passive overconsumption hypothesis? Humans show sensitivity to calories in energy-rich meals. Am J Clin Nutr. 2022;116(2):581-588. doi:10.1093/ajcn/nqac112 | Intervention/exposure; Study design
74 | Fogel A, McCrickerd K, Aris IM, et al. Eating behaviors moderate the associations between risk factors in the first 1000 days and adiposity outcomes at 6 years of age. Am J Clin Nutr. 2020;111(5):997-1006. doi:10.1093/ajcn/nqaa052 | Intervention/exposure; Study design
75 | Fogel A, Mccrickerd K, Fries LR, et al. Eating in the absence of hunger: Stability over time and associations with eating behaviours and body composition in children. Physiol Behav. 2018;192:82-89. doi:10.1016/j.physbeh.2018.03.033 | Intervention/exposure
76 | Forde CG, Fogel A, McCrickerd K. Children’s Eating Behaviors and Energy Intake: Overlapping Influences and Opportunities for Intervention. Nestle Nutr Inst Workshop Ser. 2019;91:55-67. doi:10.1159/000493695 | Study design
77 | Forman, A. Beyond 100-calorie packs: strategies to conquer portion distortion. Environmental Nutrition. 2008.31:1-6. | Study design
78 | Fox MK, Devaney B, Reidy K, Razafindrakoto C, Ziegler P. Relationship between portion size and energy intake among infants and toddlers: evidence of self-regulation. J Am Diet Assoc. 2006;106(1 Suppl 1):S77-S83. doi:10.1016/j.jada.2005.09.039 | Study design
79 | Freedman MR, Brochado C. Reducing portion size reduces food intake and plate waste. Obesity (Silver Spring). 2010;18(9):1864-1866. doi:10.1038/oby.2009.480 | Outcome
80 | Fulkerson JA, Friend S, Horning M, et al. Family Home Food Environment and Nutrition-Related Parent and Child Personal and Behavioral Outcomes of the Healthy Home Offerings via the Mealtime Environment (HOME) Plus Program: A Randomized Controlled Trial. J Acad Nutr Diet. 2018;118(2):240-251. doi:10.1016/j.jand.2017.04.006 | Intervention/exposure
81 | Gallagher R, Kirkness A, Armari E, Davidson PM. Weight management issues and strategies for people with high cardiovascular risk undertaking an Australian weight loss program: a focus group study. Nurs Health Sci. 2012;14(1):18-24. doi:10.1111/j.1442-2018.2011.00651.x | Study design
82 | Gibson EL, Wardle J. Energy density predicts preferences for fruit and vegetables in 4-year-old children. Appetite. 2003;41(1):97-98. doi:10.1016/s0195-6663(03)000771 | Outcome; Study design
83 | Gill T, Lei J, Kim HJ. Adding more portion-size options to a menu: A means to nudge consumers to choose larger portions of healthy food items. Appetite. 2022;169:105830. doi:10.1016/j.appet.2021.105830 | Outcome; Intervention/exposure
84 | Gillespie S. Healthy eating 101. Watch your portions. For weight control and good health, keep your eyes on the size. Diabetes Forecast. 2005;58(6):51-56. | Study design
85 | Godefroy V, Champel C, Trinchera L, Rigal N. Disentangling the effects of parental food restriction on child’s risk of overweight. Appetite. 2018;123:82-90. doi:10.1016/j.appet.2017.12.008 | Outcome; Intervention/exposure; Study design
86 | Godwin SL, Chambers E 4th, Cleveland L. Accuracy of reporting dietary intake using various portion-size aids in-person and via telephone. J Am Diet Assoc. 2004;104(4):585-594. doi:10.1016/j.jada.2004.01.006 | Outcome; Intervention/exposure; Study design
87 | Gómez-Zúñiga RS, Wintergerst A. Effect of food portion on masticatory parameters in 8- to 10-year-old children. J Texture Stud. 2023;54(1):67-75. doi:10.1111/jtxs.12724 | Outcome
88 | Goodman M. “Can I Have the Small?”-A Follow-up to the Resolution, “Increased Awareness and Education about Portion Size Estimation Aids”. Imprint. 2015;62(5):24-25. | Study design
89 | Greene LF, Malpede CZ, Henson CS, Hubbert KA, Heimburger DC, Ard JD. Weight maintenance 2 years after participation in a weight loss program promoting low-energy density foods. Obesity (Silver Spring). 2006;14(10):1795-1801. doi:10.1038/oby.2006.207 | Intervention/exposure
90 | Hannon SC, Hillier SE, Thondre PS, Clegg ME. Lower Energy-Dense Ready Meal Consumption Affects Self-Reported Appetite Ratings with No Effect on Subsequent Food Intake in Women. Nutrients. 2021;13(12):4505. doi:10.3390/nu13124505 | Intervention/exposure
91 | Hannum SM, Carson LA, Evans EM, et al. Use of packaged entrees as part of a weight-loss diet in overweight men: an 8-week randomized clinical trial. Diabetes Obes Metab. 2006;8(2):146-155. doi:10.1111/j.1463-1326.2005.00493.x | Duration
92 | Hannum SM, Carson L, Evans EM, et al. Use of portion-controlled entrees enhances weight loss in women. Obes Res. 2004;12(3):538-546. doi:10.1038/oby.2004.61 | Duration
93 | Hart CN, Spaeth AM, Egleston BL, et al. Effect of changes in children’s bedtime and sleep period on targeted eating behaviors and timing of caloric intake. Eat Behav. 2022;45:101629. doi:10.1016/j.eatbeh.2022.101629 | Intervention/exposure
94 | Hartstein J, Cullen KW, Reynolds KD, et al. Impact of portion-size control for school a la carte items: changes in kilocalories and macronutrients purchased by middle school students. J Am Diet Assoc. 2008;108(1):140-144. doi:10.1016/j.jada.2007.10.005 | Outcome; Intervention/exposure
95 | Haynes A, Hardman CA, Makin ADJ, Halford JCG, Jebb SA, Robinson E. Visual perceptions of portion size normality and intended food consumption: A norm range model. Food Qual Prefer. 2019;72:77-85. doi:10.1016/j.foodqual.2018.10.003 | Outcome; Intervention/exposure
96 | Helland MH, Nordbotten GL. Dietary Changes, Motivators, and Barriers Affecting Diet and Physical Activity among Overweight and Obese: A Mixed Methods Approach. Int J Environ Res Public Health. 2021;18(20):10582. doi:10.3390/ijerph182010582 | Intervention/exposure; Study design
97 | Hermans RC, Larsen JK, Herman CP, Engels RC. How much should I eat? Situational norms affect young women’s food intake during meal time. Br J Nutr. 2012;107(4):588-594. doi:10.1017/S0007114511003278 | Intervention/exposure
98 | Higginson AD, Brunstrom JM, Ferriday D, Rogers PJ, Houston AI. Dietary complexity, energy density, and obesity: An evolutionary perspective. Appetite. 2016.101:226-226. doi:10.1016/j.appet.2016.02.086 | Publication status
99 | Hollands GJ, Cartwright E, Pilling M, et al. Impact of reducing portion sizes in worksite cafeterias: a stepped wedge randomised controlled pilot trial. Int J Behav Nutr Phys Act. 2018;15(1):78. doi:10.1186/s12966-018-0705-1 | Outcome
100 | Holliday A, Batey C, Eves FF, Blannin AK. A novel tool to predict food intake: the Visual Meal Creator. Appetite. 2014;79:68-75. doi:10.1016/j.appet.2014.04.001 | Intervention/exposure
101 | Hollis JL, Williams LT, Morgan PJ, Collins CE. The 40-Something Randomised Controlled Trial improved fruit intake and nutrient density of the diet in mid-age women. Nutr Diet. 2015. 72:316-326. doi:10.1111/1747-0080.12215 | Intervention/exposure
102 | Holt SH, Brand-Miller JC, Stitt PA. The effects of equal-energy portions of different breads on blood glucose levels, feelings of fullness and subsequent food intake. J Am Diet Assoc. 2001;101(7):767-773. doi:10.1016/S0002-8223(01)00192-4 | Outcome; Intervention/exposure
103 | Hopkins M, Finlayson G, Duarte C, et al. Modelling the associations between fat-free mass, resting metabolic rate and energy intake in the context of total energy balance. Int J Obes (Lond). 2016;40(2):312-318. doi:10.1038/ijo.2015.155 | Intervention/exposure
104 | Hu H, Zuo L, Song X, et al. Longitudinal Association of Dietary Energy Density with Abdominal Obesity among Chinese Adults from CHNS 1993-2018. Nutrients. 2022;14(10):2151. doi:10.3390/nu14102151 | Country; Intervention/exposure
105 | Hua SV, Kenney EL, Miller JM, et al. Naming Matters: Prompting Smaller Portions in an Online RCT. Am J Prev Med. 2023;64(6):805-813. doi:10.1016/j.amepre.2023.01.026 | Outcome
106 | Hughes JW, Goldstein CM, Logan C, et al. Controlled testing of novel portion control plate produces smaller self-selected portion sizes compared to regular dinner plate. BMC Obes. 2017;4:30. doi:10.1186/s40608-017-0167-z | Outcome; Intervention/exposure
107 | Huyghe E, Geuens M, Vermeir I. To squeeze or not to squeeze: How squeeze tubes affect consumers’ serving sizes. Appetite. 2017;111:56-62. doi:10.1016/j.appet.2016.12.034 | Outcome; Intervention/exposure
108 | Jackson SJ, Bluck LJ, Coward WA. Use of isotopically labelled octanoic acid to assess the effect of meal size on gastric emptying. Rapid Commun Mass Spectrom. 2004;18(10):1003-1007. doi:10.1002/rcm.1440 | Outcome; Comparator
109 | James, B. L.,Roe, L. S.,Loken, E.,Rolls, B. J. Early predictors of weight loss in a 1-year behavioural weight-loss programme. Obes Sci Pract. 2018.4:20-28. doi:10.1002/osp4.149 | Intervention/exposure
110 | James BL, Roe LS, Loken E, Rolls BJ. Early predictors of weight loss in a 1-year behavioural weight-loss programme. Obes Sci Pract. 2018;4(1):20-28. Published 2018 Jan 12. doi:10.1002/osp4.149 | Intervention/exposure
111 | Jeffery RW, Abbott G, Ball K, Crawford D. Behavior and weight correlates of weight-control efforts in Australian women living in disadvantage: The READI study. Int J Behav Nutr Phys Act. 2013;10:52. doi:10.1186/1479-5868-10-52 | Intervention/exposure
112 | Johnson L, van Jaarsveld CH, Emmett PM, et al. Dietary energy density affects fat mass in early adolescence and is not modified by FTO variants. PLoS One. 2009;4(3):e4594. doi:10.1371/journal.pone.0004594 | Intervention/exposure
113 | Karfopoulou E, Mouliou K, Koutras Y, Yannakoulia M. Behaviours associated with weight loss maintenance and regaining in a Mediterranean population sample. A qualitative study. Clin Obes. 2013;3(5):141-149. doi:10.1111/cob.12028 | Study design
114 | Keenan GS, Childs L, Rogers PJ, Hetherington MM, Brunstrom JM. The portion size effect: Women demonstrate an awareness of eating more than intended when served larger than normal portions. Appetite. 2018;126:54-60. doi:10.1016/j.appet.2018.03.009 | Comparator; Intervention/exposure
115 | Keller KL, English LK, Fearnbach SN, et al. Brain response to food cues varying in portion size is associated with individual differences in the portion size effect in children. Appetite. 2018;125:139-151. doi:10.1016/j.appet.2018.01.027 | Duplicate
116 | Kelly MT. Investigation of the contribution made by food portion size to food and energy intake. 2008 | Publication status
117 | Kerameas K, Vartanian LR, Herman CP, Polivy J. The effect of portion size and unit size on food intake: Unit bias or segmentation effect?. Health Psychol. 2015;34(6):670-676. doi:10.1037/hea0000160 | Outcome
118 | Kerr JA, Jansen PW, Mensah FK, et al. Child and adult snack food intake in response to manipulated pre-packaged snack item quantity/variety and snack box size: a population-based randomized trial. Int J Obes (Lond). 2019;43(10):1891-1902. doi:10.1038/s41366-019-0407-z | Intervention/exposure
119 | Kerr MA, Rennie KL, McCaffrey TA, Wallace JM, Hannon-Fletcher MP, Livingstone MB. Snacking patterns among adolescents: a comparison of type, frequency and portion size between Britain in 1997 and Northern Ireland in 2005. Br J Nutr. 2009;101(1):122-131. doi:10.1017/S0007114508994769 | Study design
120 | Kesman RL, Ebbert JO, Harris KI, Schroeder DR. Portion control for the treatment of obesity in the primary care setting. BMC Res Notes. 2011;4:346. doi:10.1186/1756-0500-4-346 | Intervention/exposure
121 | Kim EB, Chen C, Cheon BK. Preschoolers exhibit conformity to computer-simulated food portion selection behaviors of remote peers. Appetite. 2019;139:164-171. doi:10.1016/j.appet.2019.04.028 | Comparator; Intervention/exposure
122 | Kirk S, Woo JG, Brehm B, Daniels SR, Saelens BE. Changes in Eating Behaviors of Children with Obesity in Response to Carbohydrate-Modified and Portion-Controlled Diets. Child Obes. 2017;13(5):377-383. doi:10.1089/chi.2017.0020 | Outcome; Comparator; Intervention/exposure
123 | Koenigstorfer J, Groeppel-Klein A, Kettenbaum M, Klicker K. Eat fit. Get big? How fitness cues influence food consumption volumes. Appetite. 2013;65:165-169. doi:10.1016/j.appet.2013.01.011 | Outcome; Comparator; Intervention/exposure
124 | Kohri T, Shimizu A, Suzuki T, et al. Longitudinal Study on Relationships among Snack Energy Intake, Body Mass Index, and Nutrient Intake in Japanese Children Aged 6-7 Years. J Nutr Sci Vitaminol (Tokyo). 2021;67(3):163-169. doi:10.3177/jnsv.67.163 | Intervention/exposure
125 | Koopman KE, Caan MW, Nederveen AJ, et al. Hypercaloric diets with increased meal frequency, but not meal size, increase intrahepatic triglycerides: a randomized controlled trial. Hepatology. 2014;60(2):545-553. doi:10.1002/hep.27149 | Intervention/exposure
126 | Kral TV, Stunkard AJ, Berkowitz RI, Stallings VA, Brown DD, Faith MS. Daily food intake in relation to dietary energy density in the free-living environment: a prospective analysis of children born at different risk of obesity. Am J Clin Nutr. 2007;86(1):41-47. doi:10.1093/ajcn/86.1.41 | Comparator; Intervention/exposure
127 | Kral TV, Stunkard AJ, Berkowitz RI, et al. Energy density at a buffet-style lunch differs for adolescents born at high and low risk of obesity. Eat Behav. 2009;10(4):209-214. doi:10.1016/j.eatbeh.2009.07.003 | Comparator; Intervention/exposure
128 | Kroeze W, Rongen F, Eykelenboom M, et al. A Process Evaluation of a Multi-Component Intervention in Dutch Dietetic Treatment to Improve Portion Control Behavior and Decrease Body Mass Index in Overweight and Obese Patients. Nutrients. 2018;10(11):1717. doi:10.3390/nu10111717 | Intervention/exposure; Study design
129 | Kuriyan R, Lokesh DP, D’Souza N, et al. Portion controlled ready-to-eat meal replacement is associated with short term weight loss: a randomised controlled trial. Asia Pac J Clin Nutr. 2017;26(6):1055-1065. doi:10.6133/apjcn.022017.07 | Duration
130 | Lachat CK, Verstraeten R, De Meulenaer B, et al. Availability of free fruits and vegetables at canteen lunch improves lunch and daily nutritional profiles: a randomised controlled trial. Br J Nutr. 2009;102(7):1030-1037. doi:10.1017/S000711450930389X | Intervention/exposure
131 | Lange C, Schwartz C, Hachefa C, Cornil Y, Nicklaus S, Chandon P. Portion size selection in children: Effect of sensory imagery for snacks varying in energy density. Appetite. 2020;150:104656. doi:10.1016/j.appet.2020.104656 | Intervention/exposure
132 | Leahy KE, Birch LL, Fisher JO, Rolls BJ. Reductions in entrée energy density increase children’s vegetable intake and reduce energy intake. Obesity (Silver Spring). 2008;16(7):1559-1565. doi:10.1038/oby.2008.257 | Intervention/exposure
133 | Leahy KE, Birch LL, Rolls BJ. Reducing the energy density of multiple meals decreases the energy intake of preschool-age children. Am J Clin Nutr. 2008;88(6):1459-1468. doi:10.3945/ajcn.2008.26522 | Intervention/exposure
134 | Ledikwe JH, Rolls BJ, Smiciklas-Wright H, et al. Reductions in dietary energy density are associated with weight loss in overweight and obese participants in the PREMIER trial. Am J Clin Nutr. 2007;85(5):1212-1221. doi:10.1093/ajcn/85.5.1212 | Intervention/exposure
135 | Lee A, Keung VM, Cheung GC. Compensation consumption of high-energy-density food among pre-school children leading to suboptimal intake of recommended food groups: case study in Hong Kong. Public Health. 2013;127(2):182-185. doi:10.1016/j.puhe.2012.11.001 | Study design
136 | Lee CD, Chae J, Schap TE, et al. Comparison of known food weights with image-based portion-size automated estimation and adolescents’ self-reported portion size. J Diabetes Sci Technol. 2012;6(2):428-434. Published 2012 Mar 1. doi:10.1177/193229681200600231 | Outcome
137 | Lee H, Kane I, Sereika S. Portion-control intervention for people with serious mental illness: A feasibility study [published correction appears in Perspect Psychiatr Care. 2020;56(4):858-863. doi:10.1111/ppc.12502 | Intervention/exposure
138 | Lehrman S. Energy Density May Help Control Hunger and Manage Weight: Foods with a low energy density contribute more slowly to a person’s daily energy needs. Environ Nutr. 2019.42:1-1 | Study design
139 | Leidy HJ, Apolzan JW, Mattes RD, Campbell WW. Food form and portion size affect postprandial appetite sensations and hormonal responses in healthy, nonobese, older adults. Obesity (Silver Spring). 2010;18(2):293-299. doi:10.1038/oby.2009.217 | Outcome; Comparator
140 | Levitsky DA, Pacanowski C. Losing weight without dieting. Use of commercial foods as meal replacements for lunch produces an extended energy deficit. Appetite. 2011;57(2):311-317. doi:10.1016/j.appet.2011.04.015 | Intervention/exposure
141 | Lewis NA, Earl A. Seeing more and eating less: Effects of portion size granularity on the perception and regulation of food consumption. J Pers Soc Psychol. 2018;114(5):786-803. doi:10.1037/pspp0000183 | Comparator; Intervention/exposure
142 | Libotte E, Siegrist M, Bucher T. The influence of plate size on meal composition. Literature review and experiment. Appetite. 2014;82:91-96. doi:10.1016/j.appet.2014.07.010 | Outcome; Intervention/exposure
143 | Lowe MR, Butryn ML, Thomas JG, Coletta M. Meal replacements, reduced energy density eating, and weight loss maintenance in primary care patients: a randomized controlled trial. Obesity (Silver Spring). 2014;22(1):94-100. doi:10.1002/oby.20582 | Intervention/exposure
144 | Lowe MR, Butryn ML, Zhang F. Evaluation of meal replacements and a home food environment intervention for long-term weight loss: a randomized controlled trial. Am J Clin Nutr. 2018;107(1):12-19. doi:10.1093/ajcn/nqx005 | Comparator; Intervention/exposure
145 | Lowe MR, Tappe KA, Butryn ML, et al. An intervention study targeting energy and nutrient intake in worksite cafeterias. Eat Behav. 2010;11(3):144-151. doi:10.1016/j.eatbeh.2010.01.002 | Intervention/exposure
146 | Lown DA, Fitzgibbon ML, Dyer A, Schiffer L, Gomez S, Braunschweig CL. Effect of variable energy served on 24-hour energy intake in 16 preschools, Chicago, Illinois, 2007. Prev Chronic Dis. 2011;8(3):A58. | Intervention/exposure; Study design
147 | Luszczynska A, Horodyska K, Zarychta K, Liszewska N, Knoll N, Scholz U. Planning and self-efficacy interventions encouraging replacing energy-dense foods intake with fruit and vegetable: A longitudinal experimental study. Psychol Health. 2016;31(1):40-64. doi:10.1080/08870446.2015.1070156 | Intervention/exposure
148 | MacDonald HB. Healthy bites: the problem of portion distortion. Probe (08341494). 2003. 37:[199]-[199] | Study design
149 | MacFarlane A, Cleland V, Crawford D, Campbell K, Timperio A. Longitudinal examination of the family food environment and weight status among children. Int J Pediatr Obes. 2009;4(4):343-352. doi:10.3109/17477160902846211 | Comparator; Intervention/exposure
150 | Malliga L, Sri Latha D, Pragnya A, Alekya B. MEASURING OF AN CALORIE BY USING AN FOOD RECOGINITION METHOD. J Cardiovasc Dis Res. 2023.14:1733 | Study design
151 | Mantzari E, Hollands GJ, Pechey R, Jebb S, Marteau TM. Perceived impact of smaller compared with larger-sized bottles of sugar-sweetened beverages on consumption: A qualitative analysis. Appetite. 2018;120:171-180. doi:10.1016/j.appet.2017.08.031 | Outcome; Study design
152 | Marchiori D, Corneille O, Klein O. Container size influences snack food intake independently of portion size. Appetite. 2012;58(3):814-817. doi:10.1016/j.appet.2012.01.015 | Intervention/exposure
153 | Marchiori D, Papies EK, Klein O. The portion size effect on food intake. An anchoring and adjustment process?. Appetite. 2014;81:108-115. doi:10.1016/j.appet.2014.06.018 | Outcome; Comparator; Intervention/exposure
154 | Marchiori D, Waroquier L, Klein O. Smaller food item sizes of snack foods influence reduced portions and caloric intake in young adults. J Am Diet Assoc. 2011;111(5):727-731. doi:10.1016/j.jada.2011.02.008 | Intervention/exposure
155 | Marteau TM, Hollands GJ, Shemilt I, Jebb SA. Downsizing: policy options to reduce portion sizes to help tackle obesity. BMJ. 2015;351:h5863. Published 2015 Dec 2. doi:10.1136/bmj.h5863 | Study design
156 | Martin CK, Anton SD, York-Crowe E, et al. Empirical evaluation of the ability to learn a calorie counting system and estimate portion size and food intake. Br J Nutr. 2007;98(2):439-444. doi:10.1017/S0007114507708802 | Outcome; Intervention/exposure
157 | Martin CK, Newton RL Jr, Anton SD, et al. Measurement of children’s food intake with digital photography and the effects of second servings upon food intake. Eat Behav. 2007;8(2):148-156. doi:10.1016/j.eatbeh.2006.03.003 | Intervention/exposure
158 | Marty L, Cook B, Piernas C, Jebb SA, Robinson E. Effects of Labelling and Increasing the Proportion of Lower-Energy Density Products on Online Food Shopping: A Randomised Control Trial in High- and Low-Socioeconomic Position Participants. Nutrients. 2020;12(12):3618. doi:10.3390/nu12123618 | Intervention/exposure
159 | Matheson DM, Hanson KA, McDonald TE, Robinson TN. Validity of children’s food portion estimates: a comparison of 2 measurement aids. Arch Pediatr Adolesc Med. 2002;156(9):867-871. doi:10.1001/archpedi.156.9.867 | Outcome; Intervention/exposure; Study design
160 | Matthiessen J, Fagt S, Biltoft-Jensen A, Beck AM, Ovesen L. Size makes a difference. Public Health Nutr. 2003. 6:65-72. doi:10.1079/phn2002361 | Comparator; Intervention/exposure
161 | McAteer RA, Avdovic H, Dogan L, Isenstein B. In adults with obesity, are prescribed, portion-controlled meals more effective for weight loss than dietary recommendations alone? Evidence-Based Practice. 2019.22:29-30. doi:10.1097/EBP.0000000000000480 | Study design
162 | McCall B. Smaller portions, slimmer waistline. Nephrol News & Issues. 2007. 21:7070. | Study design
163 | McConahy KL, Smiciklas-Wright H, Birch LL, Mitchell DC, Picciano MF. Food portions are positively related to energy intake and body weight in early childhood. J Pediatr. 2002;140(3):340-347. doi:10.1067/mpd.2002.122467 | Study design
164 | McConahy KL, Smiciklas-Wright H, Mitchell DC, Picciano MF. Portion size of common foods predicts energy intake among preschool-aged children. J Am Diet Assoc. 2004;104(6):975-979. doi:10.1016/j.jada.2004.03.027 | Outcome; Study design
165 | McCrickerd K, Chambers L, Yeomans MR. Does modifying the thick texture and creamy flavour of a drink change portion size selection and intake?. Appetite. 2014;73:114-120. doi:10.1016/j.appet.2013.10.020 | Intervention/exposure
166 | McCrickerd K, Lim CM, Leong C, Chia EM, Forde CG. Texture-Based Differences in Eating Rate Reduce the Impact of Increased Energy Density and Large Portions on Meal Size in Adults. J Nutr. 2017;147(6):1208-1217. doi:10.3945/jn.116.244251 | Comparator; Intervention/exposure
167 | McCrory MA, Saltzman E, Rolls BJ, Roberts SB. A twin study of the effects of energy density and palatability on energy intake of individual foods. Physiol Behav. 2006;87(3):451-459. doi:10.1016/j.physbeh.2004.10.025 | Intervention/exposure
168 | McGale LS, Smits T, Halford JCG, Harrold JA, Boyland EJ. The influence of front-of-pack portion size images on children’s serving and intake of cereal. Pediatr Obes. 2020;15(2):e12583. doi:10.1111/ijpo.12583 | Intervention/exposure
169 | McGuire B, Chambers E 4th, Godwin S, Brenner S. Size categories most effective for estimating portion size of muffins. J Am Diet Assoc. 2001;101(4):470-472. doi:10.1016/S0002-8223(01)00121-3 | Outcome; Comparator; Intervention/exposure; Study design
170 | McLoughlin R, Byrne DG, McCartney D. Pilot study: Use of a novel portion control device and dietetic app in a six-week weight management intervention. Proc Nutr Soc. 2022.81:1-1. doi:10.1017/S0029665122001124 | Publication status
171 | Meengs JS, Roe LS, Rolls BJ. Vegetable variety: an effective strategy to increase vegetable intake in adults. J Acad Nutr Diet. 2012;112(8):1211-1215. doi:10.1016/j.jand.2012.05.013 | Intervention/exposure
172 | Milà Villarroel R, Abellana Sangrà R, Padró Massaguer L, Farran Codina A. Assessment of food consumption, energy and protein intake in the meals offered in four Spanish nursing homes. Nutr Hosp. 2012;27(3):914-921. doi:10.3305/nh.2012.27.3.5730 | Comparator; Intervention/exposure; Study design
173 | Miller N, Reicks M, Redden JP, Mann T, Mykerezi E, Vickers Z. Increasing portion sizes of fruits and vegetables in an elementary school lunch program can increase fruit and vegetable consumption. Appetite. 2015;91:426-430. doi:10.1016/j.appet.2015.04.081 | Outcome
174 | Mirmiran P, Bahadoran Z, Delshad H, Azizi F. Effects of energy-dense nutrient-poor snacks on the incidence of metabolic syndrome: a prospective approach in Tehran Lipid and Glucose Study. Nutrition. 2014;30(5):538-543. doi:10.1016/j.nut.2013.09.014 | Outcome; Intervention/exposure
175 | Mitchell GL, Brunstrom JM. Everyday dietary behaviour and the relationship between attention and meal size. Appetite. 2005;45(3):344-355. doi:10.1016/j.appet.2005.06.001 | Intervention/exposure
176 | Moore H, Siroux J, Pereira B, et al. The energy content of meals with a similar macronutrient distribution may have a greater impact on appetite sensations than food preferences in adolescents with obesity: A secondary analysis. Appetite. 2023;191:107063. doi:10.1016/j.appet.2023.107063 | Outcome; Intervention/exposure
177 | Morin KH. Helping families understand portion and serving sizes. MCN Am J Matern Child Nurs. 2015;40(3):196. doi:10.1097/NMC.0000000000000136 | Study design
178 | Mrdjenovic G, Levitsky DA. Children eat what they are served: the imprecise regulation of energy intake. Appetite. 2005;44(3):273-282. doi:10.1016/j.appet.2005.01.005 | Comparator; Intervention/exposure; Study design
179 | Mushquash AR, Rasquinha AM, Friedman A, Ball GDC. Examining the Accuracy and Use of Portion Size Estimation Aids in Parents of Children With Obesity: A Randomized Controlled Trial. J Nutr Educ Behav. 2018;50(9):918-923. doi:10.1016/j.jneb.2018.06.005 | Outcome; Intervention/exposure
180 | Naaman R, Parrett A, Bashawri D, et al. Assessment of Dietary Intake Using Food Photography and Video Recording in Free-Living Young Adults: A Comparative Study. J Acad Nutr Diet. 2021;121(4):749-761.e1. doi:10.1016/j.jand.2020.09.040 | Outcome
181 | Newby PK. Examining energy density: comments on diet quality, dietary advice, and the cost of healthful eating. J Am Diet Assoc. 2006;106(8):1166-1169. doi:10.1016/j.jada.2006.06.022 | Study design
182 | Nguyen A, Chern C, Tan S. Estimated portion size versus actual intake of eight commonly consumed foods by healthy adults. Nutr Diet. 2016.73:490-497. doi:10.1111/1747-0080.12292 | Comparator; Intervention/exposure
183 | Nicklaus S, Chabanet C, Boggio V, Issanchou S. Food choices at lunch during the third year of life: increase in energy intake but decrease in variety. Acta Paediatr. 2005;94(8):1023-1029. doi:10.1111/j.1651-2227.2005.tb02040.x | Comparator; Intervention/exposure
184 | Noethlings U, Hoffmann K, Bergmann MM, Boeing H; European Investigation into Cancer and Nutrition. Portion size adds limited information on variance in food intake of participants in the EPIC-Potsdam study. J Nutr. 2003;133(2):510-515. doi:10.1093/jn/133.2.510 | Comparator; Intervention/exposure; Study design
185 | Norton GN, Anderson AS, Hetherington MM. Volume and variety: relative effects on food intake. Physiol Behav. 2006;87(4):714-722. doi:10.1016/j.physbeh.2006.01.010 | Intervention/exposure
186 | O Shahrokni R, Ferriday D, Miguel S, Laurent AL, Brunstrom JM. “This snack is too small - I’ll take a different one”: Quantifying ‘norm’ and ‘choice’ boundaries to inform effective portion-reduction strategies. Appetite. 2022;171:105886. doi:10.1016/j.appet.2021.105886 | Outcome; Intervention/exposure
187 | Ofei KT, Holst M, Rasmussen HH, Mikkelsen BE. Effect of meal portion size choice on plate waste generation among patients with different nutritional status. An investigation using Dietary Intake Monitoring System (DIMS). Appetite. 2015;91:157-164. doi:10.1016/j.appet.2015.04.043 | Health status; Intervention/exposure
188 | Ofei KT, Mikkelsen BE, Scheller RA. Validation of a novel image-weighed technique for monitoring food intake and estimation of portion size in hospital settings: a pilot study. Public Health Nutr. 2019;22(7):1203-1208. doi:10.1017/S1368980018001064 | Intervention/exposure
189 | Ong SH, Arasu K, Leow DY, Lim JX, Yang WY. Snacking and weight status in Malaysian Chinese primary school children. Hum Nutr Metab. 2023.33 | Study design
190 | Osterholt KM, Roe LS, Rolls BJ. Incorporation of air into a snack food reduces energy intake. Appetite. 2007;48(3):351-358. doi:10.1016/j.appet.2006.10.007 | Intervention/exposure
191 | Ott A, Voigt M, Sieber CC, Volkert D. The Failure of Plate Diagrams in Estimating Individualized Offered Portion Size: An enable Study. J Am Med Dir Assoc. 2021;22(3):636-641.e1. doi:10.1016/j.jamda.2020.11.012 | Comparator; Intervention/exposure
192 | Paineau D, Beaufils F, Boulier A, et al. The cumulative effect of small dietary changes may significantly improve nutritional intakes in free-living children and adults. Eur J Clin Nutr. 2010;64(8):782-791. doi:10.1038/ejcn.2010.78 | Outcome; Intervention/exposure
193 | Patel S, Vyas A, Custovic A, Murray CS. Estimated portion sizes in a school-aged population. Public Health Nutr. 2012;15(12):2193-2201. doi:10.1017/S1368980012001140 | Study design
194 | Pearce J, Wood L, Stevens L. Portion weights of food served in English schools: have they changed following the introduction of nutrient-based standards?. J Hum Nutr Diet. 2013;26(6):553-562. doi:10.1111/jhn.12067 | Outcome
195 | Pearson N, Ball K, Crawford D. Predictors of changes in adolescents’ consumption of fruits, vegetables and energy-dense snacks. Br J Nutr. 2011;105(5):795-803. doi:10.1017/S0007114510004290 | Outcome; Intervention/exposure
196 | Peng M. How does plate size affect estimated satiation and intake for individuals in normal-weight and overweight groups?. Obes Sci Pract. 2017;3(3):282-288. doi:10.1002/osp4.119 | Outcome; Intervention/exposure; Study design
197 | Poelman MP, Steenhuis IH, de Vet E, Seidell JC. The development and evaluation of an Internet-based intervention to increase awareness about food portion sizes: a randomized, controlled trial. J Nutr Educ Behav. 2013;45(6):701-707. doi:10.1016/j.jneb.2013.05.008 | Outcome; Intervention/exposure
198 | Pourshahidi LK, Kerr MA, McCaffrey TA, Livingstone MB. Influencing and modifying children’s energy intake: the role of portion size and energy density. Proc Nutr Soc. 2014;73(3):397-406. doi:10.1017/S0029665114000615 | Publication status
199 | Ptomey LT, Willis EA, Goetz JR, et al. Portion-controlled meals provide increases in diet quality during weight loss and maintenance. J Hum Nutr Diet. 2016;29(2):209-216. doi:10.1111/jhn.12296 | Intervention/exposure
200 | Radulescu A, Killian M, Kang Q, Yuan Q, Softic S. Dietary Counseling Aimed at Reducing Sugar Intake Yields the Greatest Improvement in Management of Weight and Metabolic Dysfunction in Children with Obesity. Nutrients. 2022;14(7):1500. doi:10.3390/nu14071500 | Intervention/exposure
201 | Ramsay S, Safaii S, Croschere T, Branen LJ, Wiest M. Kindergarteners’ entrée intake increases when served a larger entrée portion in school lunch: a quasi-experiment. J Sch Health. 2013;83(4):239-242. doi:10.1111/josh.12022 | Intervention/exposure
202 | Raynor HA, Van Walleghen EL, Bachman JL, Looney SM, Phelan S, Wing RR. Dietary energy density and successful weight loss maintenance. Eat Behav. 2011;12(2):119-125. doi:10.1016/j.eatbeh.2011.01.008 | Intervention/exposure; Study design
203 | Reily NM, Pinkus RT, Vartanian LR, Faasse K. Compensatory eating after exercise in everyday life: Insights from daily diary studies. PLoS One. 2023;18(3):e0282501. doi:10.1371/journal.pone.0282501 | Outcome; Intervention/exposure
204 | Reynolds JP, Ventsel M, Kosīte D, et al. Impact of decreasing the proportion of higher energy foods and reducing portion sizes on food purchased in worksite cafeterias: A stepped-wedge randomised controlled trial. PLoS Med. 2021;18(9):e1003743. doi:10.1371/journal.pmed.1003743 | Outcome
205 | Rigal N, Champel C, Hébel P, Lahlou S. Food portion at ages 8-11 and obesogeny: The amount of food given to children varies with the mother’s education and the child’s appetite arousal. Soc Sci Med. 2019;228:111-116. doi:10.1016/j.socscimed.2019.03.027 | Study design
206 | Rippin H., Hutchinson J, Jewell J, Breda JJ, Cade JE. Portion size of energy-dense foods in French and UK adults by BMI status: is there an association between portion size and BMI? Proc Nutr Soc. 2018. 77:1-1. doi:10.1017/S0029665118001878 | Study design
207 | Robertson DA, Lavin C, Lunn PD. Can Visual Cues to Portion Size Reduce the Number of Portions of Consumed? Two Randomized Controlled Trials. Ann Behav Med. 2021;55(8):746-757. doi:10.1093/abm/kaaa098 | Intervention/exposure
208 | Robinson E, Haynes A. Individual differences and moderating participant characteristics in the effect of reducing portion size on meal energy intake: Pooled analysis of three randomized controlled trials. Appetite. 2021;159:105047. doi:10.1016/j.appet.2020.105047 | Study design
209 | Robinson E, Henderson J, Keenan GS, Kersbergen I. When a portion becomes a norm: Exposure to a smaller vs. larger portion of food affects later food intake. Food Qual Prefer. 2019;75:113-117. doi:10.1016/j.foodqual.2019.02.013 | Intervention/exposure
210 | Robinson E, Oldham M, Cuckson I, Brunstrom JM, Rogers PJ, Hardman CA. Visual exposure to large and small portion sizes and perceptions of portion size normality: Three experimental studies. Appetite. 2016;98:28-34. doi:10.1016/j.appet.2015.12.010 | Outcome; Intervention/exposure
211 | Robinson E, Sheen F, Harrold J, Boyland E, Halford JC, Masic U. Dishware size and snack food intake in a between-subjects laboratory experiment. Public Health Nutr. 2016;19(4):633-637. doi:10.1017/S1368980015001408 | Intervention/exposure
212 | Robinson E, Haynes A. A universal driver of human eating behaviour? Individual differences in energy intake in response to reducing main meal portion size. Appetite. 2021.157. doi:10.1016/j.appet.2020.104892 | Publication status
213 | Roe BE, Apolzan JW, Qi D, Allen HR, Martin CK. Plate waste of adults in the United States measured in free-living conditions. PLoS One. 2018;13(2):e0191813. doi:10.1371/journal.pone.0191813 | Comparator; Intervention/exposure
214 | Roe LS, Keller KL, Rolls BJ. Food Properties and Individual Characteristics Influence Children’s Intake Across Multiple Days of Weighed Assessments in Childcare Programs. J Nutr. 2023;153(5):1646-1655. doi:10.1016/j.tjnut.2023.03.025 | Outcome
215 | Rolls BJ, Roe LS, Keller KL. Children’s Energy Intake Generally Increases in Response to the Energy Density of Meals but Varies with the Amounts and Types of Foods Served. Am J Clin Nutr. 2024;119(1):185-195. doi:10.1016/j.ajcnut.2023.10.019 | Intervention/exposure
216 | Rolls BJ, Bell EA, Waugh BA. Increasing the volume of a food by incorporating air affects satiety in men. Am J Clin Nutr. 2000;72(2):361-368. doi:10.1093/ajcn/72.2.361 | Intervention/exposure
217 | Rolls BJ, Drewnowski A, Ledikwe JH. Changing the energy density of the diet as a strategy for weight management. J Am Diet Assoc. 2005;105(5 Suppl 1):S98-S103. doi:10.1016/j.jada.2005.02.033 | Study design
218 | Rolls BJ, Roe LS, Beach AM, Kris-Etherton PM. Provision of foods differing in energy density affects long-term weight loss. Obes Res. 2005;13(6):1052-1060. doi:10.1038/oby.2005.123 | Intervention/exposure
219 | Rolls BJ, Roe LS, Halverson KH, Meengs JS. Using a smaller plate did not reduce energy intake at meals. Appetite. 2007;49(3):652-660. doi:10.1016/j.appet.2007.04.005 | Intervention/exposure
220 | Rousset S, Médard S, Fleury G, Fardet A, Goutet O, Lacomme P. Energy Intake Evaluation by a Learning Approach Using the Number of Food Portions and Body Weight. Foods. 2021;10(10):2273. Published 2021 Sep 26. doi:10.3390/foods10102273 | Intervention/exposure; Study design
221 | Saeki K, Otaki N, Kitagawa M, et al. Development and validation of nutrient estimates based on a food-photographic record in Japan. Nutr J. 2020;19(1):104. doi:10.1186/s12937-020-00615-y | Intervention/exposure
222 | Saha S, Lozano CP, Broyles S, Martin CK, Apolzan JW. Assessing the Initial Validity of the PortionSize App to Estimate Dietary Intake Among Adults: Pilot and Feasibility App Validation Study. JMIR Form Res. 2022;6(6):e38283. doi:10.2196/38283 | Outcome; Comparator; Intervention/exposure
223 | Salazar Vázquez BY, Salazar Vázquez MA, López Gutiérrez G, et al. Control of overweight and obesity in childhood through education in meal time habits. The ‘good manners for a healthy future’ programme. Pediatr Obes. 2016;11(6):484-490. doi:10.1111/ijpo.12091 | Intervention/exposure
224 | Santos I, Vieira PN, Silva MN, Sardinha LB, Teixeira PJ. Weight control behaviors of highly successful weight loss maintainers: the Portuguese Weight Control Registry. J Behav Med. 2017;40(2):366-371. doi:10.1007/s10865-016-9786-y | Study design
225 | Savage JS, Haisfield L, Fisher JO, Marini M, Birch LL. Do children eat less at meals when allowed to serve themselves?. Am J Clin Nutr. 2012;96(1):36-43. doi:10.3945/ajcn.112.035261 | Intervention/exposure
226 | Schlundt DG, Buchowski MS, Hargreaves MK, Hankin JH, Signorello LB, Blot WJ. Separate estimates of portion size were not essential for energy and nutrient estimation: results from the Southern Community Cohort food-frequency questionnaire pilot study. Public Health Nutr. 2007;10(3):245-251. doi:10.1017/S1368980007258574 | Study design
227 | Schwartz J, Riis J, Elbel B, Ariely D. Inviting consumers to downsize fast-food portions significantly reduces calorie consumption. Health Aff (Millwood). 2012;31(2):399-407. doi:10.1377/hlthaff.2011.0224 | Study design
228 | Schwartz MB, O’Connell M, Henderson KE, Middleton AE, Scarmo S. Testing Variations on Family-Style Feeding To Increase Whole Fruit and Vegetable Consumption among Preschoolers in Child Care. Child Obes. 2015;11(5):499-505. doi:10.1089/chi.2015.0038 | Intervention/exposure
229 | Schwartz RP. Super-size kids’ meals lead to super-size kids. N C Med J. 2002;63(6):305-307. | Publication status; Study design
230 | Scisco JL, Blades C, Zielinski MJ, Muth ER. Dividing a fixed portion into more pieces leads to larger portion size estimates of JELL-O squares. Perception. 2012;41(8):988-990. doi:10.1068/p7199 | Outcome; Intervention/exposure
231 | Scott B, Perumean-Chaney S, St. Jeor S. Relationship of body mass index to energy density and diet composition in a free-living population. Top Clin Nutr. 2002. 17:38-46. doi:10.1097/00008486-200209000-00005 | Intervention/exposure
232 | Shah M, Schroeder R, Winn W, Adams-Huet B. A pilot study to investigate the effect of plate size on meal energy intake in normal weight and overweight/obese women. J Hum Nutr Diet. 2011;24(6):612-615. doi:10.1111/j.1365277X.2011.01210.x | Intervention/exposure
233 | Sharps MA, Thomas E, Blissett JM. Using pictorial nudges of fruit and vegetables on tableware to increase children’s fruit and vegetable consumption. Appetite. 2020;144:104457. doi:10.1016/j.appet.2019.104457 | Intervention/exposure
234 | Sheen F, Hardman CA, Robinson E. Food waste concerns, eating behaviour and body weight. Appetite. 2020;151:104692. doi:10.1016/j.appet.2020.104692 | Comparator; Intervention/exposure
235 | Sheen F, Hardman CA, Robinson E. Plate-clearing tendencies and portion size are independently associated with main meal food intake in women: A laboratory study. Appetite. 2018;127:223-229. doi:10.1016/j.appet.2018.04.020 | Outcome
236 | Shemirani F, Djafarian K, Fotouhi A, et al. Effect of Paleolithic-based low-carbohydrate vs. moderate-carbohydrate diets with portion-control and calorie-counting on CTRP6, asprosin and metabolic markers in adults with metabolic syndrome: A randomized clinical trial. Clin Nutr ESPEN. 2022;48:87-98. doi:10.1016/j.clnesp.2021.11.013 | Comparator; Intervention/exposure
237 | Siegel RM, Neidhard MS, Kirk S. A comparison of low glycemic index and staged portion-controlled diets in improving BMI of obese children in a pediatric weight management program. Clin Pediatr (Phila). 2011;50(5):459-461. doi:10.1177/0009922810394839 | Comparator; Intervention/exposure
238 | Sim AY, Lim EX, Forde CG, Cheon BK. Personal relative deprivation increases self-selected portion sizes and food intake. Appetite. 2018;121:268-274. doi:10.1016/j.appet.2017.11.100 | Outcome; Intervention/exposure
239 | Sitzman K. Expanding food portions contribute to overweight and obesity. AAOHN J. 2004;52(8):356. | Study design
240 | Small L, Bonds-McClain D, Vaughan L, Melnyk B, Gannon A, Thompson S. A parent-directed portion education intervention for young children: Be Beary Healthy. J Spec Pediatr Nurs. 2012;17(4):312-320. doi:10.1111/j.1744-6155.2012.00340.x | Study design
241 | Smethers AD, Roe LS, Sanchez CE, Zuraikat FM, Keller KL, Rolls BJ. Both increases and decreases in energy density lead to sustained changes in preschool children’s energy intake over 5 days. Physiol Behav. 2019;204:210-218. doi:10.1016/j.physbeh.2019.02.042 | Intervention/exposure
242 | Smith KR. Weight loss through behavior modification. Health Care Food Nutr Focus. 2005. 22:8-11. | Study design
243 | Smith L, Conroy K, Wen H, Rui L, Humphries D. Portion size variably affects food intake of 6-year-old and 4-year-old children in Kunming, China. Appetite. 2013;69:31-38. doi:10.1016/j.appet.2013.05.010 | Outcome
244 | Soini S, Mustajoki P, Eriksson JG. Weight loss methods and changes in eating habits among successful weight losers. Ann Med. 2016;48(1-2):76-82. doi:10.3109/07853890.2015.1136428 | Comparator; Intervention/exposure
245 | Sorenson KE, Rice J, Droms Hatch C. A question of food intake: The impact of living arrangement and meal factors on total daily caloric intake. Health Mark Q. 2020;37(2):124-137. doi:10.1080/07359683.2020.1754048 | Publication status; Intervention/exposure
246 | Sossen L, Bonham M, Porter J. An investigation of recommended serve food portions and attaining energy and protein requirements in older adults living in residential care. J Hum Nutr Diet. 2021;34(2):374-383. doi:10.1111/jhn.12824 | Comparator; Intervention/exposure
247 | Spill MK, Birch LL, Roe LS, Rolls BJ. Hiding vegetables to reduce energy density: an effective strategy to increase children’s vegetable intake and reduce energy intake. Am J Clin Nutr. 2011;94(3):735-741. doi:10.3945/ajcn.111.015206 | Intervention/exposure
248 | Spiro A, Chambers L, Miller R. Childhood obesity and portion control in preschool children. Nursing in Practice: The Journal for Today’s Primary Care Nurse. 2016.1-3 | Publication status; Study design
249 | Sterling W, Crosbie C, Shaw N, Martin S. The Use of the Plate-by-Plate Approach for Adolescents Undergoing Family-Based Treatment. J Acad Nutr Diet. 2019;119(7):1075-1084. doi:10.1016/j.jand.2018.06.011 | Study design
250 | Stroebele N, Ogden LG, Hill JO. Do calorie-controlled portion sizes of snacks reduce energy intake?. Appetite. 2009;52(3):793-796. doi:10.1016/j.appet.2009.02.015 | Outcome
251 | Stromberg SE, Janicke DM. The relationship between mother to child calories served and maternal perception of hunger. J Hum Nutr Diet. 2016;29(3):290-297. doi:10.1111/jhn.12309 | Intervention/exposure
252 | Stubbs J, Brogelli D, Pallister C, Avery A, McConnon A, Lavin J. Behavioural and motivational factors associated with weight loss and maintenance in a commercial weight management programme. Open Obes J. 2012.4:35-43. doi:10.2174/1876823701204010035 | Study design
253 | Sud S, Tamayo NC, Faith MS, Keller KL. Increased restrictive feeding practices are associated with reduced energy density in 4-6-year-old, multi-ethnic children at ad libitum laboratory test-meals. Appetite. 2010;55(2):201-207. doi:10.1016/j.appet.2010.05.089 | Intervention/exposure
254 | Syrad H, Llewellyn CH, Johnson L, et al. Meal size is a critical driver of weight gain in early childhood. Sci Rep. 2016;6:28368. Published 2016 Jun 20. doi:10.1038/srep28368 | Intervention/exposure
255 | Tal A, Grinstein A, Kleijnen M. Weighing heavy: Heavy serving dishes increase food serving. PLoS One. 2023;18(8):e0288956. Published 2023 Aug 25. doi:10.1371/journal.pone.0288956 | Intervention/exposure
256 | Temple JL, Giacomelli AM, Roemmich JN, Epstein LH. Habituation and within-session changes in motivated responding for food in children. Appetite. 2008;50(2-3):390-396. doi:10.1016/j.appet.2007.09.005 | Outcome; Intervention/exposure
257 | Temple JL, Ziegler AM, Crandall AK, Mansouri T, Epstein LH. Sensitization of the reinforcing value of food: a novel risk factor for overweight in adolescents. Int J Obes (Lond). 2020;44(9):1918-1927. doi:10.1038/s41366-020-0641-4 | Intervention/exposure; Study design
258 | Temple JL, Ziegler AM, Crandall AK, et al. Sensitization of the reinforcing value of high energy density foods is associated with increased zBMI gain in adolescents. Int J Obes (Lond). 2022;46(3):581-587. doi:10.1038/s41366-021-01007-w | Intervention/exposure
259 | Tey SL, Salleh N, Henry CJ, Forde CG. Effects of Consuming Preloads with Different Energy Density and Taste Quality on Energy Intake and Postprandial Blood Glucose. Nutrients. 2018;10(2):161. Published 2018 Jan 31. doi:10.3390/nu10020161 | Intervention/exposure
260 | Thompson D, Ferry RJ Jr, Cullen KW, Liu Y. Improvement in Fruit and Vegetable Consumption Associated with More Favorable Energy Density and Nutrient and Food Group Intake, but not Kilocalories. J Acad Nutr Diet. 2016;116(9):1443-1449. doi:10.1016/j.jand.2016.05.002 | Intervention/exposure
261 | Tong H, Morris E, Jebb SA, Koutoukidis DA. Identifying and measuring the behavioural, dietary, and physical activity components of weight management consultations delivered by general practice nurses in routine care. BMC Fam Pract. 2021;22(1):65. Published 2021 Apr 7. doi:10.1186/s12875-021-01403-1 | Outcome; Intervention/exposure; Study design
262 | Torbahn G, Gellhaus I, Koch B, et al. Reduction of Portion Size and Eating Rate Is Associated with BMI-SDS Reduction in Overweight and Obese Children and Adolescents: Results on Eating and Nutrition Behaviour from the Observational KgAS Study. Obes Facts. 2017;10(5):503-516. doi:10.1159/000480517 | Study design
263 | Tsai AG, Felton S, Wadden TA, Hosokawa PW, Hill JO. A randomized clinical trial of a weight loss maintenance intervention in a primary care population. Obesity (Silver Spring). 2015;23(10):2015-2021. doi:10.1002/oby.21224 | Comparator; Intervention/exposure
264 | Ueland O, Cardello AV, Merrill EP, Lesher LL. Effect of portion size information on food intake. J Am Diet Assoc. 2009;109(1):124-127. doi:10.1016/j.jada.2008.10.002 | Comparator; Intervention/exposure
265 | Urban LE, McCrory MA, Rasmussen H, et al. Independent, additive effects of five dietary variables on ad libitum energy intake in a residential study. Obesity (Silver Spring). 2014;22(9):2018-2025. doi:10.1002/oby.20798 | Intervention/exposure
266 | Vadiveloo M, Parker H, Raynor H. Increasing low-energy-dense foods and decreasing high-energy-dense foods differently influence weight loss trial outcomes. Int J Obes (Lond). 2018;42(3):479-486. doi:10.1038/ijo.2017.303 | Intervention/exposure
267 | Vakili M, Jafarirad S, Abedi P, Amani R, Cheraghian B. Visual Cues and Food Intake: Distortion Power of Plate and Spoon Size on Overweight and Obese University Staff. Int J Prev Med. 2019;10:82. doi:10.4103/ijpvm.IJPVM_557_17 | Intervention/exposure
268 | van den Akker K, Bongers P, Hanssen I, Jansen A. Validation of prospective portion size and latency to eat as measures of reactivity to snack foods. Appetite. 2017;116:480-486. doi:10.1016/j.appet.2017.05.049 | Comparator; Intervention/exposure
269 | InterAct Consortium, van den Berg SW, van der A DL, et al. The association between dietary energy density and type 2 diabetes in Europe: results from the EPIC-InterAct Study. PLoS One. 2013;8(5):e59947. Published 2013 May 16. doi:10.1371/journal.pone.0059947 | Outcome; Intervention/exposure; Study design
270 | van Egmond-Fröhlich AW, Weghuber D, de Zwaan M. Association of symptoms of attention-deficit/hyperactivity disorder with physical activity, media time, and food intake in children and adolescents. PLoS One. 2012;7(11):e49781. doi:10.1371/journal.pone.0049781 | Study design
271 | van Ittersum K, Wansink B. Do children really prefer large portions? Visual illusions bias their estimates and intake. J Am Diet Assoc. 2007;107(7):1107-1110. doi:10.1016/j.jada.2007.05.020 | Study design
272 | van Kleef E, Mitsuru S, Wansink B. Serving Bowl Selection Biases the Amount of Food Served. J Nutr Educ Behav. 2012.44(1):66-70. doi:10.1016/j.jneb.2011.03.001 | Intervention/exposure
273 | Vandenbroele J, Van Kerckhove A, Zlatevska N. Portion size effects vary: The size of food units is a bigger problem than the number. Appetite. 2019.(140):27-40. doi:10.1016/j.appet.2019.04.025 | Outcome
274 | Vargas-Alvarez MÁ, Brunstrom JM, Díaz AE, Navas-Carretero S, Martínez JA, Almiron-Roig E. Portion control tableware differentially impacts eating behaviour in women with and without overweight. Appetite. 2023.(185):106542. doi:10.1016/j.appet.2023.106542 | Intervention/exposure
275 | Vartanian LR, Reily NM, Spanos S, Herman CP, Polivy J. Self-reported overeating and attributions for food intake. Psychol Health. 2017;32(4):483-492. doi:10.1080/08870446.2017.1283040 | Outcome
276 | Venema TAG, Kroese FM, Verplanken B, de Ridder DTD. The (bitter) sweet taste of nudge effectiveness: The role of habits in a portion size nudge, a proof of concept study. Appetite. 2020;151:104699. doi:10.1016/j.appet.2020.104699 | Outcome; Intervention/exposure
277 | Vermeer WM, Leeuwis FH, Koprulu S, Zouitni O, Seidell JC, Steenhuis IH. The process evaluation of two interventions aimed at portion size in worksite cafeterias. J Hum Nutr Diet. 2012;25(2):180-188. doi:10.1111/j.1365277X.2011.01219.x | Outcome; Study design
278 | Vermeer WM, Steenhuis IH, Leeuwis FH, Bos AE, de Boer M, Seidell JC. View the label before you view the movie: a field experiment into the impact of portion size and Guideline Daily Amounts labelling on soft drinks in cinemas. BMC Public Health. 2011;11:438. Published 2011 Jun 6. doi:10.1186/1471-2458-11-438 | Intervention/exposure
279 | Vermeer WM, Steenhuis IH, Leeuwis FH, Heymans MW, Seidell JC. Small portion sizes in worksite cafeterias: do they help consumers to reduce their food intake?. Int J Obes (Lond). 2011;35(9):1200-1207. doi:10.1038/ijo.2010.271 | Outcome
280 | Vermote M, Versele V, Stok M, et al. The effect of a portion size intervention on French fries consumption, plate waste, satiety and compensatory caloric intake: an on-campus restaurant experiment. Nutr J. 2018;17(1):43. Published 2018 Apr 13. doi:10.1186/s12937-018-0352-z | Outcome
281 | Versluis I, Papies EK. The Role of Social Norms in the Portion Size Effect: Reducing Normative Relevance Reduces the Effect of Portion Size on Consumption Decisions. Front Psychol. 2016;7:756. Published 2016 May 31. doi:10.3389/fpsyg.2016.00756 | Outcome
282 | Wansink B, Johnson KA. The clean plate club: about 92% of self-served food is eaten. Int J Obes (Lond). 2015;39(2):371-374. doi:10.1038/ijo.2014.104 | Comparator; Intervention/exposure; Study design
283 | Wansink B, Kim J. Bad popcorn in big buckets: portion size can influence intake as much as taste [published correction appears in J Nutr Educ Behav. 2017 Sep;49(8):714. doi: 10.1016/j.jneb.2017.05.340]. J Nutr Educ Behav. 2005;37(5):242-245. doi:10.1016/s1499-4046(06)60278-9 | Outcome
284 | Wansink B, Painter JE, North J. Bottomless bowls: why visual cues of portion size may influence intake. Obes Res. 2005;13(1):93-100. doi:10.1038/oby.2005.12 | Intervention/exposure
285 | Wansink B, van Ittersum K. Portion size me: downsizing our consumption norms. J Am Diet Assoc. 2007;107(7):1103-1106. doi:10.1016/j.jada.2007.05.019 | Publication status; Study design
286 | Warkentin S, Fildes A, Oliveira A. Appetitive behaviors and body composition in school-age years: Bi-directional analyses in a population-based birth cohort. Appetite. 2022;168:105770. doi:10.1016/j.appet.2021.105770 | Intervention/exposure
287 | Webb K, Rutihauser I, Knezevic N. Foods, nutrients and portions consumed by a sample of Australian children aged 16-24 months. Nutr Diet. 2008.(65):56-65. doi:10.1111/j.1747-0080.2007.00224.x | Study design
288 | Wee CC, Davis RB, Phillips RS. Stage of readiness to control weight and adopt weight control behaviors in primary care. J Gen Intern Med. 2005;20(5):410-415. doi:10.1111/j.1525-1497.2005.0074.x | Study design
289 | Westerterp-Plantenga MS. Modulatory factors in the effect of energy density on energy intake. Br J Nutr. 2004;92 Suppl 1:S35-S39. doi:10.1079/bjn20041140 | Publication status; Study design
290 | Wilkinson LL, Brunstrom JM. Conditioning ‘fullness expectations’ in a novel dessert. Appetite. 2009;52(3):780-783. doi:10.1016/j.appet.2009.02.009 | Publication status; Intervention/exposure
291 | Wilkinson LL, Ferriday D, Bosworth ML, et al. Keeping Pace with Your Eating: Visual Feedback Affects Eating Rate in Humans. PLoS One. 2016;11(2):e0147603. doi:10.1371/journal.pone.0147603 | Intervention/exposure
292 | Wilkinson LL, Hinton EC, Fay SH, Ferriday D, Rogers PJ, Brunstrom JM. Computer-based assessments of expected satiety predict behavioural measures of portionsize selection and food intake. Appetite. 2012;59(3):933-938. doi:10.1016/j.appet.2012.09.007 | Comparator
293 | Williams RA, Roe LS, Rolls BJ. Comparison of three methods to reduce energy density. Effects on daily energy intake. Appetite. 2013;66:75-83. doi:10.1016/j.appet.2013.03.004 | Intervention/exposure
294 | Wolever TMS, van Klinken BJ, Spruill SE, Jenkins AL, Chu Y, Harkness L. Effect of serving size and addition of sugar on the glycemic response elicited by oatmeal: A randomized, cross-over study. Clin Nutr ESPEN. 2016;16:48-54. doi:10.1016/j.clnesp.2016.07.003 | Outcome; Intervention/exposure
295 | Yeomans MR, Gould NJ, Leitch M, Mobini S. Effects of energy density and portion size on development of acquired flavour liking and learned satiety. Appetite. 2009;52(2):469-478. doi:10.1016/j.appet.2008.12.010 | Comparator; Intervention/exposure
296 | Yip W, Wiessing KR, Budgett S, Poppitt SD. Using a smaller dining plate does not suppress food intake from a buffet lunch meal in overweight, unrestrained women. Appetite. 2013;69:102-107. doi:10.1016/j.appet.2013.05.017 | Intervention/exposure
297 | Young MD, Lubans DR, Collins CE, Callister R, Plotnikoff RC, Morgan PJ. Behavioral mediators of weight loss in the SHED-IT community randomized controlled trial for overweight and obese men. Ann Behav Med. 2015;49(2):286-292. doi:10.1007/s12160-014-9657-0 | Intervention/exposure
298 | Zhao L, Teong XT, Liu K, et al. Eating architecture in adults at increased risk of type 2 diabetes: associations with body fat and glycaemic control. Br J Nutr. 2022;128(2):324-333. doi:10.1017/S0007114521002944 | Outcome; Intervention/exposure; Study design
299 | Zhou S, Shapiro MA, Wansink B. The audience eats more if a movie character keeps eating: An unconscious mechanism for media influence on eating behaviors [published correction appears in Appetite. 2019 Feb 1;133:442. doi: 10.1016/j.appet.2018.11.020]. Appetite. 2017;108:407-415. doi:10.1016/j.appet.2016.10.028 | Intervention/exposure
300 | Zhou X, Zhang L. The Influence of Dietary Energy Density on Childhood Obesity. Iran J Public Health. 2014;43(11):1587-1588. | Intervention/exposure; Study design
301 | Zimmerman AR, Ferriday D, Davies SR, et al. “What time is my next meal?” delay-discounting individuals choose smaller portions under conditions of uncertainty. Appetite. 2017;116:284-290. doi:10.1016/j.appet.2017.05.019 | Outcome; Intervention/exposure
302 | Zimmerman AR, Mason A, Rogers PJ, Brunstrom JM. Obese and overweight individuals are less sensitive to information about meal times in portion-size judgements. Int J Obes (Lond). 2018;42(4):905-910. doi:10.1038/ijo.2017.275 | Outcome; Intervention/exposure
303 | Zuraikat FM, St-Onge MP, Makarem N, Boege HL, Xi H, Aggarwal B. Evening Chronotype Is Associated with Poorer Habitual Diet in US Women, with Dietary Energy Density Mediating a Relation of Chronotype with Cardiovascular Health. J Nutr. 2021;151(5):1150-1158. doi:10.1093/jn/nxaa442 | Outcome; Intervention/exposure
304 | Żurakowski A, Zahorska-Markiewicz B, Olszanecka-Glinianowicz M, Kocelak P. Effect of Meal Volume on Hunger and Satiety in Obese Subjects: Volume of meal and satiety. EJIFCC. 2006;17(4):167-176. Published 2006 Dec 1. | Outcome