# Appendix 2 Literature search strategy

This search was first run on June 26, 2023, and then periodically run using NESR’s continuous evidence monitoring methods^*^ until January 2024.

* USDA Nutrition Evidence Systematic Review Branch. Chapter 10: Continuous Evidence Monitoring. In: USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview.

[underlined: Database: PubMed]

Provider: U.S. National Library of Medicine

Date(s) Searched: June 26, 2023 (initial search); June 26, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 2 Search for PubMed

Search # | Concept | String
#1 | Portion size | Portion Size[MeSH] OR Serving Size[MeSH] OR serving size*[tiab] OR “size portion”[tiab:~3] OR “size portions”[tiab:~3] OR “size meal”[tiab:~3] OR “size meals”[tiab:~3] OR “size snack”[tiab:~3] OR “size snacks”[tiab:~3] OR “meal portion*”[tiab] OR “food portion*”[tiab] OR “portion control*”[tiab] OR “energy dens*”[tiab] OR “Caloric dens*”[tiab] OR “calorie dens*”[tiab] OR “nutrient dens*”[tiab] OR preportioned[tiab] OR “pre portioned”[tiab]
#2 | Growth, body composition, and risk of obesity | ”Adipose Tissue”[Mesh] OR “Body Composition”[Mesh] OR “Body Weights and Measures”[MeSH:NoExp] OR “Body Fat Distribution”[Mesh] OR “Body Mass Index”[Mesh] OR “Body Size”[Mesh] OR “Skinfold Thickness”[Mesh] OR “Waist-Hip Ratio”[Mesh] OR “Overnutrition”[Mesh] OR “Growth”[Mesh:NoExp] OR anthropometr*[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR lean mass[tiab] OR obese[tiab] OR obesity[tiab] OR underweight[tiab] OR overweight[tiab] OR weight status[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR calf circumference[tiab] OR neck circumference[tiab] OR thigh circumference[tiab] OR waist circumference[tiab] OR waist to hip ratio[tiab] OR waist hip ratio[tiab] OR body mass index[tiab] OR BMI[tiab] OR adipos*[tiab] OR body weight[tiab] OR body height[tiab] OR body size[tiab] OR body composition[tiab] OR overnutrition[tiab] OR wasting[tiab] OR healthy weight[tiab] OR skin fold[tiab] OR skin folds[tiab] OR skinfold[tiab] OR skinfolds[tiab] OR “Weight Reduction Programs”[Mesh] OR “Body-Weight Trajectory”[Mesh] OR “Weight Gain”[MeSH] OR “Weight Loss”[MeSH:NoExp] OR “Diet, Reducing”[Mesh] OR weight gain*[tiab] OR diet reduc*[tiab] OR weight cycling[tiab] OR weight decreas*[tiab] OR weight watch*[tiab] OR weight control*[tiab] OR weight retention[tiab] OR weight management[tiab] OR “maintain weight”[tiab:~4] OR “maintains weight”[tiab:~4] OR “maintaining weight”[tiab:~4] OR “maintained weight”[tiab:~4] OR “weight maintenance”[tiab:~4] OR “reduce weight”[tiab:~4] OR “reduces weight”[tiab:~4] OR “reducing weight”[tiab:~4] OR “reduced weight”[tiab:~4] OR “weight reduction”[tiab:~4] OR “lose weight”[tiab:~4] OR “loses weight”[tiab:~4] OR “losing weight”[tiab:~4] OR “lost weight”[tiab:~4] OR “weight loss”[tiab:~4] OR “change weight”[tiab:~4] OR “changes weight”[tiab:~4] OR “changing weight”[tiab:~4] OR “changed weight”[tiab:~4] OR “Growth Charts”[Mesh] OR growth chart*[tiab]OR stunting[tiab] OR stunted[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR length for age[tiab] OR weight for length[tiab] OR failure to thrive[tiab]
#3 | Energy intake | ”Energy Intake”[MeSH] OR “energy intake”[tiab] OR “calorie intake”[tiab] OR “caloric intake”[tiab] OR “total energy”[tiab] OR “total calorie*”[tiab] OR “total caloric*”[tiab] OR “energy consum*”[tiab] OR “calorie consum*”[tiab] OR “caloric consum*”[tiab]
#4 | | #1 AND (#2 OR #3)
#5 | Limits | #4 NOT (”Animals”[Mesh] NOT (”Animals”[Mesh] AND “Humans”[Mesh])); NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Filters applied: English, from 2000/1/1 - 3000/12/12.

[underlined: Database: Embase]

Provider: Elsevier

Date(s) Searched: June 26, 2023 (initial search); June 26, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 3 Search for Embase

Search # | Concept | String
#1 | Portion Size | ‘Portion Size’/exp OR ‘serving size*’:ab,ti OR (size NEAR/4 (portion* OR meal* OR snack*)):ab,ti OR ‘meal portion*’:ab,ti OR ‘food portion*’:ab,ti OR ‘portion control*’:ab,ti OR ‘energy dens*’:ab,ti OR ‘Caloric dens*’:ab,ti OR ‘calorie dens*’:ab,ti OR ‘nutrient dens*’:ab,ti OR preportioned:ab,ti OR ‘pre portioned’:ab,ti
#2 | Growth, body composition, and risk of obesity | ‘adipose tissue’/exp OR ‘body composition’/exp OR ‘anthropometry’/de OR ‘body mass’/exp OR ‘anthropometric parameters’/exp OR ‘skinfold thickness’/exp OR ‘overnutrition’/exp OR ‘growth’/de OR ‘anthropometr*’:ab,ti OR ‘body fat’:ab,ti OR ‘fat mass’:ab,ti OR ‘fat free mass’:ab,ti OR ‘lean mass’:ab,ti OR ‘obese’:ab,ti OR ‘obesity’:ab,ti OR ‘underweight’:ab,ti OR ‘overweight’:ab,ti OR ‘weight status’:ab,ti OR ‘head circumference’:ab,ti OR ‘arm circumference’:ab,ti OR ‘calf circumference’:ab,ti OR ‘neck circumference’:ab,ti OR ‘thigh circumference’:ab,ti OR ‘waist circumference’:ab,ti OR ‘waist to hip ratio’:ab,ti OR ‘waist hip ratio’:ab,ti OR ‘body mass index’:ab,ti OR ‘BMI’:ab,ti OR ‘adipos*’:ab,ti; OR ‘body weight’:ab,ti OR ‘body height’:ab,ti OR ‘body size’:ab,ti OR ‘body composition’:ab,ti OR ‘overnutrition’:ab,ti OR ‘wasting’:ab,ti OR ‘healthy weight’:ab,ti OR ‘skin fold*’:ab,ti OR ‘skinfold*’:ab,ti OR ‘body weight management’/exp OR ‘body weight change’/exp OR ‘weight gain*’:ab,ti OR ‘diet reduc*’:ab,ti OR ‘weight cycling’:ab,ti OR ‘weight watch*’:ab,ti OR ‘weight control*’:ab,ti OR ‘weight retention’:ab,ti OR ‘weight management’:ab,ti, kw OR (weight NEAR/4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*)):ab,ti OR ‘weight chart’/exp OR ‘growth chart*’:ab,ti OR stunting:ab,ti OR stunted:ab,ti OR ‘weight for height’:ab,ti OR ‘stature for age’:ab,ti OR ‘weight for age’:ab,ti OR ‘height for age’:ab,ti OR ‘length for age’:ab,ti OR ‘weight for length’:ab,ti OR ‘ failure to thrive’:ab,ti
#3 | Energy intake | ‘caloric intake’/exp OR ‘energy intake’:ab,ti OR ‘calorie intake’:ab,ti OR ‘caloric intake’:ab,ti OR ‘total energy’:ab,ti OR ‘total calorie*’:ab,ti OR ‘total caloric*’:ab,ti OR ‘energy consum*’:ab,ti OR ‘calorie consum*’:ab,ti OR ‘caloric consum*’:ab,ti
#4 | | #1 AND (#2 OR #3)
#5 | Limits | #4 AND ([article]/lim OR [article in press]/lim); NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)); AND [english]/lim; NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’:ab,ti OR ‘retraction notice’:ti OR ‘retracted publication’:ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR ‘practice guideline’:ti OR ‘protocol’:ti) AND [2000-2024]/py

[underlined: Database: Cochrane Central Register of Controlled Trials (CENTRAL)]

Provider: John Wiley & Sons

Date(s) Searched: June 26, 2023 (initial search); June 26, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 4 Search for Cochrane CENTRAL

Search # | Concept | String
#1 | Portion size | [mh “Portion Size”] OR [mh “Serving Size”] OR ((serving NEXT size*) OR (size NEAR/4 (portion* OR meal* OR snack*)) OR (meal NEXT portion*) OR (food NEXT portion*) OR (portion NEXT control*) OR (energy NEXT dens*) OR (Caloric NEXT dens*) OR (calorie NEXT dens*) OR (nutrient NEXT dens*) OR preportioned OR “pre portioned”):ti,ab,kw
#2 | Growth, body composition, and risk of obesity | ([mh “Adipose Tissue”] OR [mh “Body Composition”] OR [mh ^”Body Weights and Measures”] OR [mh “Body Fat Distribution”] OR [mh “Body Mass Index”] OR [mh “Body Size”] OR [mh “Skinfold Thickness”] OR [mh “Waist-Hip Ratio”] OR [mh Overnutrition] OR [mh ^Growth] OR anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds):ti,ab,kw OR ([mh “Weight Reduction Programs”] OR [mh “Body-Weight Trajectory”] OR [mh “Weight Gain”] OR [mh ^“Weight Loss”] OR [mh “Diet, Reducing”] OR “diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”):ti,ab,kw; OR ((weight NEAR/4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*)) OR [mh “Growth Charts”] OR “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “ failure to thrive”):ti,ab,kw
#3 | Energy intake | [mh “Energy Intake”] OR (”energy intake” OR “calorie intake” OR “caloric intake” OR “total energy” OR (total NEXT calorie*) OR (total NEXT caloric*) OR (energy NEXT consum*) OR (calorie NEXT consum*) OR (caloric NEXT consum*)):ti,ab,kw
#4 | | #1 AND (#2 OR #3); In Trials. Word variations have been searched.; Year First Published: 2000-2024

[underlined: Database: CINAHL]

Provider: EBSCO

Date(s) Searched: June 26, 2023 (initial search); June 26, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 5 Search for CINAHL

Search # | Concept | String
#1 | Portion size | (MH “Portion Size”) OR AB (“serving size*” OR (size NEAR/4 (portion* OR meal* OR snack*)) OR “meal portion*” OR “food portion*” OR “portion control*” OR “energy dens*” OR “Caloric dens*” OR “calorie dens*” OR “nutrient dens*” OR preportioned OR “pre portioned”) OR TI (“serving size*” OR (size NEAR/4 (portion* OR meal* OR snack*)) OR “meal portion*” OR “food portion*” OR “portion control*” OR “energy dens*” OR “Caloric dens*” OR “calorie dens*” OR “nutrient dens*” OR preportioned OR “pre portioned”)
#2 | Growth, body composition, and risk of obesity | (MH “Adipose Tissue+”) OR (MH “Body Composition+”) OR (MH “Body Weights and Measures”) OR (MH “Arm Circumference”) OR (MH “Body Height”) OR (MH “Body Mass Index”) OR (MH “Body Size”) OR (MH “Body Weight+”) OR (MH “Crown-Rump Length”) OR (MH “Waist Circumference”) OR (MH “Waist-Hip Ratio”) OR (MH “Skinfold Thickness”) OR (MH “Obesity+”) OR (MH “Overnutrition”) OR (MH “Growth”) OR (TI anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight”; OR “skin fold” OR “skin folds” OR skinfold OR skinfolds) OR (AB anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds) OR (MH “Weight Reduction Programs”) OR (MH “Body Weight Changes”) OR (MH “Weight Gain+”) OR (MH “Weight Loss”) OR (MH “Diet, Reducing”) OR (TI “diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”) OR (AB “diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”) OR (TI (weight N4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*))) OR (AB (weight N4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*))) OR (TI “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”) OR (AB “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”)
#3 | Energy intake | (MH “Energy Intake”) OR TI (”energy intake” OR “calorie intake” OR “caloric intake” OR “total energy” OR “total calorie*” OR “total caloric*” OR “energy consum*” OR “calorie consum*” OR “caloric consum*”) OR AB (”energy intake” OR “calorie intake” OR “caloric intake” OR “total energy” OR “total calorie*” OR “total caloric*” OR “energy consum*” OR “calorie consum*” OR “caloric consum*”)
#4 | | S1 AND (S2 OR S3)
#5 | Limits | S4 NOT ((MH “Animals+”) OR (MH “Animal Studies”)); NOT ((MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication)); Limiters - English Language, Expanders - Apply equivalent subject; Published Date: 20000101-20240109