# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body Mass Index
FNS: Food and Nutrition Service
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
NICHD: National Institutes of Child Human Development
NRCT: Non-randomized Controlled Trial
RCT: Randomized Controlled Trial
USDA: United States Department of Agriculture