# References of the articles included in the systematic review

1 Alves-Santos N, Cocate PG, Cocate P, . Prepregnancy Dietary Patterns and Their Association with Perinatal Outcomes: A Prospective Cohort Study. J Acad Nutr Diet. 2019;119(9):1439–1451. doi:10.1016/j.jand.2019.02.016 31053516
2 Barchitta M, Magnano San Lio R, La Rosa MC, . The Effect of Maternal Dietary Patterns on Birth Weight for Gestational Age: Findings from the MAMI-MED Cohort. Nutrients. 2023;15:1922. doi:10.3390/nu15081922 37111140
3 Berube L, Deierlein AL, Woolf K, Messito MJ, Gross RS. Prenatal Dietary Patterns and Associations With Weight-Related Pregnancy Outcomes in Hispanic Women With Low Incomes. Child Obes. 2023;20(3):198–207. doi:10.1089/chi.2022.0227 37126780
4 Bodnar LM, Kirkpatrick SI, Parisi SM, Jin Q, Naimi AI. Periconceptional Dietary Patterns and Adverse Pregnancy and Birth Outcomes. J Nutr. 2024;154:680–690. doi:10.1016/j.tjnut.2023.12.013 38122847
5 Chatzi L, Mendez M, Garcia R, . Mediterranean diet adherence during pregnancy and fetal growth: INMA (Spain) and RHEA (Greece) mother-child cohort studies. Br J Nutr. 2012;107(1):135–45. doi:10.1017/S0007114511002625 21733314
6 Chen L-W, Aubert AM, Shivappa N, . Associations of maternal dietary inflammatory potential and quality with offspring birth outcomes: An individual participant data pooled analysis of 7 European cohorts in the ALPHABET consortium. PLoS Med. 2021;18(1):1–22. doi:10.1371/journal.pmed.1003491
7 Chia A-R, de Seymour JV, Colega M, . A vegetable, fruit, and white rice dietary pattern during pregnancy is associated with a lower risk of preterm birth and larger birth size in a multiethnic Asian cohort: the Growing Up in Singapore Towards healthy Outcomes (GUSTO) cohort study. Am J Clin Nutr. 2016;104(5):1416–1423. doi:10.3945/ajcn.116.133892 27733407
8 de Seymour JV, Beck KL, Conlon CA, . An Investigation of the Relationship Between Dietary Patterns in Early Pregnancy and Maternal/Infant Health Outcomes in a Chinese Cohort. Front Nutr. 2022;9:775557. doi:10.3389/fnut.2022.775557 35529458
9 Díaz-López A, Díaz-Torres S, Martín-Luján F, Basora J, Arija V. Prenatal adherence to the Mediterranean diet decreases the risk of having a small-for-gestational-age baby, ECLIPSES study. Sci Rep. 2022;12(1):13794. doi:10.1038/s41598-022-17957-8 35963881
10 Emond JA, Karagas MR, Baker ER, Gilbert-Diamond D. Better Diet Quality during Pregnancy Is Associated with a Reduced Likelihood of an Infant Born Small for Gestational Age: An Analysis of the Prospective New Hampshire Birth Cohort Study. J Nutr. 2018;148(1):22–30. doi:10.1093/jn/nxx005 29378041
11 Englund-Ögge L, Brantsæter A, Juodakis J, . Associations between maternal dietary patterns and infant birth weight, small and large for gestational age in the Norwegian Mother and Child Cohort Study. Eur J Clin Nutr. 2019;73(9):1270–1282. doi:10.1038/s41430-018-0356-y 30459338
12 Flynn AC, Seed PT, Patel N, . Dietary patterns in obese pregnant women; influence of a behavioral intervention of diet and physical activity in the UPBEAT randomized controlled trial. Int J Behav Nutr Phys Act. 2016;13(1):124. doi:10.1186/s12966-016-0450-2 27894316
13 Fulay AP, Rifas-Shiman SL, Oken E, Perng W. Associations of the dietary approaches to stop hypertension (DASH) diet with pregnancy complications in Project Viva. Eur J Clin Nutr. 2018;72(10):1385–1395. doi:10.1038/s41430-017-0068-8 29339829
14 Gonzalez-Nahm S, Hoyo C, Østbye T, Neelon B, Allen C, Benjamin-Neelon S. Associations of maternal diet with infant adiposity at birth, 6 months and 12 months. BMJ Open. 2019;9(9):1–7. doi:10.1136/bmjopen-2019-030186
15 Grieger JA, Grzeskowiak LE, Clifton VL. Preconception dietary patterns in human pregnancies are associated with preterm delivery. J Nutr. 2014;144(7):1075–80. doi:10.3945/jn.114.190686 24790026
16 Hajianfar H, Esmaillzadeh A, Feizi A, Shahshahan Z, Azadbakht L. Major Maternal Dietary Patterns during Early Pregnancy and Their Association with Neonatal Anthropometric Measurement. Biomed Res Int. 2018;2018:1–11. doi:10.1155/2018/4692193
17 Hillesund ER, Bere E, Haugen M, Øverby NC. Development of a New Nordic Diet score and its association with gestational weight gain and fetal growth - a study performed in the Norwegian Mother and Child Cohort Study (MoBa). Public Health Nutr. 2014;17(9):1909–18. doi:10.1017/S1368980014000421 24685309
18 Hillesund ER, Bere E, Sagedal LR, . Pre-pregnancy and early pregnancy dietary behavior in relation to maternal and newborn health in the Norwegian Fit for Delivery study - a post hoc observational analysis. Food Nutr Res. 2018;62(1654-661X (Print))doi:10.29219/fnr.v62.1273
19 Hrolfsdottir L, Halldorsson TI, Birgisdottir BE, Hreidarsdottir IT, Hardardottir H, Gunnarsdottir I. Development of a dietary screening questionnaire to predict excessive weight gain in pregnancy. Matern Child Nutr. 2019;15(1):e12639. doi:10.1111/mcn.12639 30033533
20 Hwang J, Shin D, Kim H, Kwon O. Association of maternal dietary patterns during pregnancy with small-for-gestational-age infants: Korean Mothers and Children’s Environmental Health (MOCEH) study. Am J Clin Nutr. 2022;115(2):471–481. doi:10.1093/ajcn/nqab340 34625785
21 Knudsen VK, M. O-BI, Mikkelsen TB, Wolff S, Olsen SF. Major dietary patterns in pregnancy and fetal growth. Eur J Clin Nutr. 2008;62(4):463–70. doi:10.1038/sj.ejcn.1602745 17392696
22 Lecorguillé M, Lioret S, de Lauzon-Guillain B, . Association between Dietary Intake of One-Carbon Metabolism Nutrients in the Year before Pregnancy and Birth Anthropometry. Nutrients. 2020;12(3):838. doi:10.3390/nu12030838 32245126
23 Li Y, Zhou X, Zhang Y, . Association of Maternal Dietary Patterns With Birth Weight and the Mediation of Gestational Weight Gain: A Prospective Birth Cohort. Front Nutr. 2021;8(2296-861X (Print)):782011. doi:10.3389/fnut.2021.782011 34901129
24 Lipsky LA-O, Cummings J, Siega-Riz AM, Nansel T. Relationships of pregnancy and postpartum diet quality with offspring birth weight and weight status through 12 months. Obesity. 2023;(12):3008–3015. doi:10.1002/oby.23891 37731285
25 Lu MS, Chen QZ, He JR, . Maternal Dietary Patterns and Fetal Growth: A Large Prospective Cohort Study in China. Nutrients. 2016;8(5):257. doi:10.3390/nu8050257 27136584
26 Makarem N, Chau K, Miller EC, . Association of a Mediterranean Diet Pattern With Adverse Pregnancy Outcomes Among US Women. JAMA Netw Open. 2022;5(12):e2248165. doi:10.1001/jamanetworkopen.2022.48165 36547978
27 Maldonado L, Farzan SF, Toledo-Corral CM, . A Vegetable, Oil, and Fruit Dietary Pattern in Late Pregnancy is Linked to Reduced Risks of Adverse Birth Outcomes in a Predominantly Low-Income Hispanic and Latina Pregnancy Cohort. J Nutr. 2022;152(12):2837–2846. doi:10.1093/jn/nxac209
28 Miele M, Souza R, Calderon IM, . Maternal Nutrition Status Associated with Pregnancy-Related Adverse Outcomes. Nutrients. 2021;13(7):2398. doi:10.3390/nu13072398 34371906
29 Mikeš O, Brantsæter A, Knutsen HK, . Dietary patterns and birth outcomes in the ELSPAC pregnancy cohort. J Epidemiol Community Health. 2022;76(6):613–619. doi:10.1136/jech-2020-215716 34921058
30 Navarro P, Mehegan J, Murrin C, Kelleher CC, Phillips C. Adherence to the Healthy Eating Index-2015 across Generations Is Associated with Birth Outcomes and Weight Status at Age 5 in the Lifeways Cross-Generation Cohort Study. Int J Obes. 2020;44(11):2213–2224. doi:10.1038/s41366-020-00652-x
31 Navarro P, Mehegan J, Murrin CA-O, Kelleher CC, Phillips CM. Associations between a maternal healthy lifestyle score and adverse offspring birth outcomes and childhood obesity in the Lifeways Cross-Generation Cohort Study. Nutrients. 2019;11(4):928. doi:10.3390/nu11040928 31027168
32 Okubo H, Miyake Y, Sasaki S, . Maternal dietary patterns in pregnancy and fetal growth in Japan: the Osaka Maternal and Child Health Study. Br J Nutr. 2012;107(10):1526–33. doi:10.1017/S0007114511004636 21929833
33 Okubo H, Nakayama SF. Periconceptional maternal diet quality influences blood heavy metal concentrations and their effect on low birth weight: the Japan Environment and Children’s Study. Environ Int. 2023;173:107808. doi:10.1016/j.envint.2023.107808 36827813
34 Paknahad ZA-O, Fallah A, Moravejolahkami AR. Maternal Dietary Patterns and Their Association with Pregnancy Outcomes. Clin Nutr Res. 2019;8(1):64–73. doi:10.7762/cnr.2019.8.1.64 30746349
35 Parisi F, Savasi VM, i Bartolo I, Mandia L, Cetin I. Associations between First Trimester Maternal Nutritional Score, Early Markers of Placental Function, and Pregnancy Outcome. Nutrients. Jun 17 2020;12(6):1799. doi:10.3390/nu12061799 32560356
36 Poon AK, Yeung E, Boghossian N, Albert PS, Zhang C. Maternal Dietary Patterns during Third Trimester in Association with Birthweight Characteristics and Early Infant Growth. Scientifica. 2013;doi:10.1155/2013/786409
37 Reyes-López MA, González-Leyva C, Rodríguez-Cano AM, . Diet Quality Is Associated with a High Newborn Size and Reduction in the Risk of Low Birth Weight and Small for Gestational Age in a Group of Mexican Pregnant Women: An Observational Study. Nutrients. 2021;13(6):1853. doi:10.3390/nu13061853 34071717
38 Rifas-Shiman SL, Rich-Edwards J. W. Kleinman KP, Oken E, Gillman MW. Dietary quality during pregnancy varies by maternal characteristics in Project Viva: a US cohort. J Am Diet Assoc. 2009;109(6):1004–1011. doi:10.1016/j.jada.2009.03.001 19465182
39 Rodríguez-Bernal CL, Rebagliato M, Iñiguez C, . Diet quality in early pregnancy and its effects on fetal growth outcomes: the Infancia y Medio Ambiente (Childhood and Environment) Mother and Child Cohort Study in Spain. Am J Clin Nutr. 2010;91:1659–66. doi:10.3945/ajcn.2009.28866 20410088
40 Santos IDS, Crivellenti LC, Franco LJ, Sartorelli DS. Relationship between the quality of the pregnant woman’s diet and birth weight: a prospective cohort study. Eur J Clin Nutr. Dec 2021;75(12):1819–1828. doi:10.1038/s41430-021-00894-6 33742155
41 Sun C, Wu Y, Cai Z, . Maternal Dietary Diversity and Small for Gestational Age: The Effect Modification by Pre-Pregnancy Body Mass Index and Gestational Weight Gain in a Prospective Study within Rural Sichuan, China (2021-2022). Nutrients. 2023;15(17):3669. doi:10.3390/nu15173669 37686701
42 Teixeira J, Hoffman DJ, Castro T, . Pre-pregnancy dietary pattern is associated with newborn size: results from ProcriAr study. Br J Nutr. 2021;126(6):903–912. doi:10.1017/S0007114520004778 33256857
43 Xu H, Buchanan L, Wang Y, Phongsavan P, Baur LA, Wen L. Associations of dietary and sedentary behaviours of pregnant women with their children’s birth weight: findings from the CHAT trial in Australia. Public Health Nutr. 2023;26(12):2859–2867. doi:10.1017/S1368980023002161 37842791
44 Yamashita T, Obara T, Yonezawa Y, . Dietary patterns before and during pregnancy and small for gestational age in Japan: a prospective birth cohort study. Nutr J. 2022;21(1):57. doi:10.1186/s12937-022-00808-7 36114492
45 Yee LM, Silver RM, Haas DM, . Quality of periconceptional dietary intake and maternal and neonatal outcomes. Am J Obstet Gynecol. 2020;223(1):121. doi:10.1016/j.ajog.2020.01.042
46 Yisahak S, Mumford SL, Grewal J, . Maternal diet patterns during early pregnancy in relation to neonatal outcomes. Am J Clin Nutr. 2021;114(1):358–367. doi:10.1093/ajcn/nqab019 33742192
47 Zhang Y, Zhao Y, Duan Y, . Effects of prepregnancy dietary patterns on infant birth weight: a prospective cohort study. J Matern Fetal Neonatal Med. 2023;36(2):2273216. doi:10.1080/14767058.2023.2273216 37904502
48 Zhu Y, Hedderson MM, Sridhar S, Xu F, Feng J, Ferrara A. Poor diet quality in pregnancy is associated with increased risk of excess fetal growth: a prospective multi-racial/ethnic cohort study. Int J Epidemiol. 2019;48(2):423–432. doi:10.1093/ije/dyy285 30590563
49 Zulyniak M, de Souza RJ, Shaikh M, . Does the impact of a plant-based diet during pregnancy on birth weight differ by ethnicity? A dietary pattern analysis from a prospective Canadian birth cohort alliance. BMJ Open. 2017;7(11)doi:10.1136/bmjopen-2017-017753
50 Ancira-Moreno M, O’Neill MS, Rivera-Dommarco J, . Dietary patterns and diet quality during pregnancy and low birthweight: The PRINCESA cohort. Matern Child Nutr. Jul 2020;16(3):e12972. doi:10.1111/mcn.12972 32037674
51 Al Wattar BH, Dodds J, Placzek A, . Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): A pragmatic multicentre randomised trial. PLoS Med. 2019;16(7):e1002857. doi:10.1371/journal.pmed.1002857 31335871
52 Assaf-Balut C, García de la Torre N, Durán A, . A Mediterranean diet with additional extra virgin olive oil and pistachios reduces the incidence of gestational diabetes mellitus (GDM): A randomized controlled trial: The St. Carlos GDM prevention study. PLoS One. 2017;12(10):e0185873. doi:10.1371/journal.pone.0185873 29049303
53 Assaf-Balut C, García de la Torre N, Duran A, . A Mediterranean Diet with an Enhanced Consumption of Extra Virgin Olive Oil and Pistachios Improves Pregnancy Outcomes in Women Without Gestational Diabetes Mellitus: A Sub-Analysis of the St. Carlos Gestational Diabetes Mellitus Prevention Study. Ann Nutr Metab. 2019;74(1):69–79. doi:10.1159/000495793 30554220
54 Crovetto F, Crispi F, Casas R, . Effects of Mediterranean Diet or Mindfulness-Based Stress Reduction on Prevention of Small-for-Gestational Age Birth Weights in Newborns Born to At-Risk Pregnant Individuals: The IMPACT BCN Randomized Clinical Trial. JAMA. 2021;326(21):2150–2160.34874420
55 Dodd J, Deussen A, Louise J. A Randomised Trial to Optimise Gestational Weight Gain and Improve Maternal and Infant Health Outcomes through Antenatal Dietary, Lifestyle and Exercise Advice: The OPTIMISE Randomised Trial. Nutrients. 2019;11(12):2911. doi:10.3390/nu11122911 31810217
56 Gallagher D, Rosenn B, Toro-Ramos T, . Greater Neonatal Fat-Free Mass and Similar Fat Mass Following a Randomized Trial to Control Excess Gestational Weight Gain. Obesity. 2018;26(3):578–587. doi:10.1002/oby.22079 29464905
57 Khoury J, Henriksen TC, B. Tonstad, S. Effect of a cholesterol-lowering diet on maternal, cord, and neonatal lipids, and pregnancy outcome: a randomized clinical trial. Am J Obstet Gynecol. 2005;193(4):1292–301. doi:10.1016/j.ajog.2005.05.016 16202717
58 Melero V, García de la Torre N, Assaf-Balut C, . Effect of a Mediterranean Diet-Based Nutritional Intervention on the Risk of Developing Gestational Diabetes Mellitus and Other Maternal-Fetal Adverse Events in Hispanic Women Residents in Spain. Nutrients. 2020;12(11):3505. doi:10.3390/nu12113505 33202607
59 Van Horn L, Peaceman A, Kwasny M, . Dietary Approaches to Stop Hypertension Diet and Activity to Limit Gestational Weight: Maternal Offspring Metabolics Family Intervention Trial, a Technology Enhanced Randomized Trial. Am J Prev Med. 2018;55(5):603–614. doi:10.1016/j.amepre.2018.06.015 30262148
60 Zhao L, Zhang P, Zheng Q, Deka A, Choudhury R, Rastogi S. Does a MediDiet With Additional Extra Virgin Olive Oil and Pistachios Reduce the Incidence of Gestational Diabetes? Endocr Pract. 2022;28(2):135–141. doi:10.1016/j.eprac.2021.08.010 34481972