# Summary of conclusion statements and grades

The Committee answered the systematic review question, “What is the relationship between dietary patterns consumed during pregnancy and birth weight?”, with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Small-for-gestational age

Dietary patterns consumed during pregnancy that are characterized by higher intakes of vegetables, fruits, legumes, nuts and seeds, grains, fish/seafood, dairy, and unsaturated fats, and lower intakes of red and processed meat, added sugars, and saturated fats may be associated with lower risk of small-for-gestational age in infants. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

### Large-for-gestational age, low birth weight, and macrosomia

A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during pregnancy and risk of large-for-gestational age, low birth weight, and macrosomia in infants because of substantial concerns with consistency, risk of bias, and generalizability in the body of evidence. (Grade: Grade Not Assignable)

## Research recommendations

To more adequately assess the relationship between dietary patterns during pregnancy and birth weight, additional research is needed that should:

1. Include populations representative of all Americans, such as diversity in race and/or ethnicity, socioeconomic position, disability status, and gender identity. Of note, only 1 of the included studies reported including participants who were American Indian or Alaska Native.
2. Clearly describe characteristics related to health disparities (e.g., racial or ethnic group, religion, SEP, gender, age, or mental health; cognitive, sensory, or physical disability; sexual orientation or gender identity; geographic location; substance use; or other characteristics historically linked to discrimination or exclusion).
3. Conduct well-designed and sufficiently powered trials where the isolated effect of the dietary pattern on the outcome can be determined and where the dietary patterns and comparator patterns are fully described. Include details pertaining to the food groups to enhance ability to make comparisons with other studies.
4. Consider stratifying analyses by race and/or ethnicity or SEP (or other social determinants of health) or account for these and other key confounders in methods and/or analyses.
5. Examine LGA and SGA using cut-offs that are clinically relevant for the U.S. population.
6. Include strong justification when controlling for variables that occur after the start of the exposure period (i.e., pregnancy) that could have been affected by the exposure, such as gestational weight gain.
7. Administer dietary assessments as early as possible in and multiple times throughout pregnancy, use validated and reliable assessment methods, such as multiple 24 hour recalls and food frequency questionnaires validated for the population, and provide clear information on the period of time captured by the assessments.
8. In addition to other planned analyses, evaluate the dietary pattern against existing indices of dietary quality (e.g., HEI) to facilitate comparison across studies.
9. Collect information on prenatal supplementation and consider supplementation in study design and/or analytic plan.

Table 8 Evidence examining the relationship between dietary patterns consumed during pregnancy and birth weight^a^

Study Characteristics | Intervention or Exposure, Outcome | Results | Confounders, Funding, Summary
RCT
Al Wattar, 2019^51^; RCT, Parallel-arm, United Kingdom, ESTEEM (Effect of Simple Targeted Diet in Pregnant Women With Metabolic Risk Factors on Pregnancy Outcomes); Baseline N=1,252; Analytic N= 1,137 (Attrition: 9%); - Age (y): IG: 31.4±5.2, CG: 30.9±5.2; >40 (%): IG: 3.9, CG: 3.1; - Race/Ethnicity (%): White: IG: 36.6, CG: 35.5; Asian: IG: 43.4, CG: 44.1; Black: IG: 16.4, CG: 17.2; Other: IG: 3.7; CG: 3.3; - Baseline BMI (%): 25-29.9: IG: 16.7, CG: 16.7; ≥30: IG: 69.1, CG: 69.6; - Current HDP (%): PE: IG: 6.2, CG: 4.6; - Current DM (%): GDM: IG: 17.6, CG: 24.9, p=0.01 | IG vs CG; 24 HR at baseline (~18 GW);; ESTEEM Q at 20, 24, 28, 32, and 36 GW; DP Description:; - CG: Received usual care and antenatal dietary advice as per U.K. national recommendations; - IG: High intake of nuts, extra virgin olive oil, fruit, vegetables, nonrefined grains, and legumes; moderate to high consumption of fish; low to moderate intake of poultry and dairy products; low consumption of red meat and processed meat; and avoidance of sugary drinks, fast food, and food rich in animal fat. Participants provided with 30 g/d of mixed nuts and 0.5 L/wk of EVOO.; Adherence: ESTEEM Q score did not differ between groups at baseline but was significantly higher in IG vs CG after the intervention.; - Positive components: Olive oil (as main fat and svg/d); Nuts (including peanuts) Vegetables; Fruit (including juice); Pulses; Fish or shellfish; White meat over red meat; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial sweets or pastries; Outcomes:; - SGA: <10%ile, Customized and population based; - Very SGA: Cut-off NR, Customized and population based; - LGA: Cut-off NR, Customized and population based; Customized: BW centile using customized charts adjusting for maternal height, weight, parity, gestation at delivery and ethnic origin; Population based: Population based BW centile | SGA; Multivariable logistic regression; OR (95% CI); [underlined: All participants]; Customized: NR; Population based: 0.73 (0.51, 1.04), p=0.08; [underlined: BMI ≥30]: 0.65 (0.41, 1.03), p≥0.05; [underlined: Raised TG]: 1.00 (0.53, 1.91), 0.60 (0.35, 1.02), p≥0.05; p for interaction=0.22; [underlined: Chronic HTN]: 2.02 (0.58, 7.02), p≥0.05; [underlined: No chronic HTN:] 0.66 (0.43, 0.99), p<0.05; p for interaction=0.09; Very SGA; Multivariable logistic regression; OR (95% CI); [underlined: All participants]; Customized: 0.84 (0.43, 1.63), p=0.60; Population based: 0.96 (0.57, 1.61), p=0.87; LGA; Multivariable logistic regression; OR (95% CI); [underlined: All participants]; Customized: 1.23 (0.86, 1.78), p=0.26; Population based: 1.01 (0.69, 1.49), p=0.94 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP; Other covariates: Personal history of GDM; Family history of hypertensive disorders; Family history of DM; Personal history of stillbirth; Recruitment center; Funding: Barts Charity; California Walnut Commission and Blue Diamond Growers donated walnuts and almonds, respectively; Summary: A simple, individualized, Mediterranean-style DP supplemented with mixed nuts and EVOO reduced risk of SGA in participants without chronic HTN compared to usual care. Results neared statistical significance for a reduction of risk of SGA in all metabolically at risk participants, but there was no effect seen in participants with BMI ≥30, BMI <30, normal TG, raised TG, or chronic HTN. There was no effect of the intervention on LGA.
Assaf-Balut, 2017^52^; RCT, Parallel-arm, Spain, The St. Carlos GDM Prevention Study; Analytic N= 874 (Attrition: 13%); - Age (y): CG: 32.7±5.3; IG: 33.2±5.0; - Race/Ethnicity (%): White: CG: 67.8, IG: 69.0; Hispanic: CG: 28.4, IG: 28.6; Other: CG: 3.8, IG: 2.4; - SEP:; - ○ Education (%): Elementary: CG: 10.8, IG: 6.8; University: CG: 50.2, IG: 50.4; - ○ Employment (%): CG: 75.2, IG: 78.0; - Pre-pregnancy BMI: CG: 23.3±4.0; IG: 22.9±3.6; - Current HDP (%):; - ○ GHTN: CG: 4.3, IG: 3.0; - ○ PE: CG: 2.5; IG: 1.6; - Current DM (%): GDM: CG: 23.4, IG: 17.1, p=0.012; - Smoking (%): CG: 8.0, IG: 8.6 | IG vs CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - Both the IG and CG given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg/wk legumes, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals. They were also instructed to be physically active and walk >30 min/d.; - IG recommended to consume ≥40 mL/d of EVOO and a handful (25-30 g/d) of pistachios and were provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ between groups at baseline. Scores significantly increased over time in both groups, but scores remaining significantly higher in the IG compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries; Outcomes:; - SGA: BW <10%ile according to national charts; - LGA: BW >90%ile | SGA; Logistic regression; RR (95% CI); 0.21 (0.08, 0.54), p=0.001; LGA; Logistic regression; RR (95% CI); 0.19 (0.07, 0.57), p=0.003 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Fondo Europeo de Desarrollo Regiona; Summary: A MedDiet supplemented with EVOO and pistachios reduced risk of LGA and SGA compared to lower alignment with a MedDiet. There was not sufficient data to assess the statistical significance of the effect on macrosomia.
Assaf-Balut, 2019^53^; RCT, Spain, The St. Carlos GDM Prevention Study; Analytic N=697 (Attrition: 15%); - Age (y): CG: 32.54±5.29; IG: 32.92±4.92; - Race/Ethnicity (%): White: CG: 67.1, IG: 67.8; Hispanic: CG: 29.1, IG: 30.3; Other: CG: 3.9, IG: 1.9; - SEP:; - ○ Education (%): Elementary: CG: 7.6, IG: 6.1; University: CG: 50.1, IG: 51.4; - ○ Employment (%): CG: 75.3, IG: 79.2; - Pre-pregnancy BMI: CG: 22.9±3.8, IG: 22.4±3.3; - Current HDP (%):; - ○ GHTN: CG: 3.3, IG: 3.6; - ○ PE: CG: 1.2, IG: 1.9; - Current DM (%): GDM: 0.0; - Smoking (%): CG: 7.4; IG: 8.3 | IG vs CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - Both the IG and CG given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg/wk legumes, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals. They were also instructed to be physically active and walk >30 min/d.; - IG recommended to consume ≥40 mL/d of EVOO and a handful (25-30 g/d) of pistachios and were provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ at baseline. Scores significantly increased over time in both groups, but scores remained significantly higher in the IG compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries; Outcomes:; - SGA: BW <10%ile according to national charts; - LGA: BW >90%ile | SGA; Logistic regression; RR (95% CI); 0.26 (0.08, 0.80), p=0.018; LGA; Logistic regression; RR (95% CI); 0.25 (0.07, 0.90), p=0.034 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Among normoglycemic participants, a MedDiet supplemented with EVOO and pistachios reduced risk of LGA and SGA compared to lower alignment with a MedDiet.
Crovetto, 2021^54^; RCT, Parallel-arm, Spain, IMPACT BCN (Improving Mothers for a Better Prenatal Care Trial Barcelona); Baseline N=814; Analytic N=793; (Attrition: 3%); - Age (y): Median (IQR): IG: 37.2 (34.5-40.4); CG: 37 (33.2-40.5); - Race/Ethnicity (%): White: IG: 80.1, CG: 78.8; Latin American: IG: 13.8, CG: 15.2; Maghreb: IG: 2.0, CG: 2.2; Asian: IG: 2.0, CG: 2.0; Black: IG: 2.0, CG: 1.7; - SEP:; - ○ SES status (%): High: IG: 59.7; CG: 57.1; Low: IG: 5.1; CG: 7.2; - Pre-pregnancy BMI: IG: 24±4.8; CG: 23.9±4.8; - Current HDP (%):; - ○ GHTN: IG: 2.0; CG: 2.3; - ○ PE: IG: 5.6; CG: 9.3, p=0.05; - ○ Eclampsia: IG: 0.3; CG: 0.0; - Current DM (%):; - ○ DM: IG: 5.4; CG: 4.0; - ○ GDM: IG: 12.2; CG: 7.5, p=0.03; - Smoking (%): IG: 6.9; CG: 9.5 | IG vs CG; FFQ and 7d diet journal at: 19-23.6 GW and 34-36 GW; DP Description:; - IG: Participants received dietary training and personalized advice to increase adherence to the Mediterranean diet, including increasing intake of whole grain cereals (≥5 svg/d); vegetables and dairy products (≥3 svg/d); fresh fruit (≥2 svg/d) including natural fruit juices; and legumes, nuts, fish, and white meat (≥3 svg/wk), as well as olive oil use for cooking and dressings. They also received olive oil (2 L/mo) and walnuts (450 g/mo).; - CG: Participants received usual care per institutional protocols.; Adherence: Mediterranean diet scores were similar between groups at baseline, but significantly increased in the IG at follow-up compared to the CG.; - Positive components: EVOO; walnuts; vegetables; fresh fruit; dairy products; whole grains; sofrito; legumes; fish; fatty fish; white meat; - Negative components: Refined grains; red meat; processed meat; soda drinks; commercial bakery foods, sweets, and pastries; butter, margarine, or cream; Outcomes:; - SGA: BW <10%ile according to local standards; - Severe SGA: BW <3%ile; - LGA: BW >90%ile | SGA; Logistic regression; Risk difference (95% CI); OR (95% CI) according to-intention-totreat (ITT) analysis; −7.9 (−13.6, −2.6); 0.58 (0.40, 0.84), p=0.004; OR (95% CI) according to per-protocol (PP) analysis; IG: Participants with high dietary adherence (3 point increase in diet score); 0.56 (0.36, 0.86), p=0.009; Severe SGA; Logistic regression; Risk difference (95% CI); OR (95% CI) according to ITT analysis; −4.7 (−8.3, −1.0); 0.50 (0.28, 0.87), p=0.01; OR (95% CI) according to PP analysis; IG: Participants with high dietary adherence (3 point increase in diet score); 0.36 (0.17, 0.75), p=0.01; LGA; Chi-squared, %; IG: 9.4; CG: 9.5, p=0.98 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP; Funding: “La Caixa” Foundation; Cerebra Foundation for the Brain Injured Child; The Agency for Management of University and Research Grants; Centro de Investigaciones Biomédicas en Red sobre Enfermedades Raras; Summary: In participants at high risk for SGA, a Mediterranean-style DP supplemented with walnuts and EVOO reduced risk of SGA and severe SGA compared to usual care in both the (ITT) and the (PP) analyses. There was no statistically significant difference between groups in risk of LGA.
Dodd, 2019^55^; RCT, Parallel-arm, Australia, OPTIMISE; Analytic N=633 (Attrition: 1%); - Age (y): 31.53±4.76; - Race/Ethnicity (%): White: 67.46; Asian: 15.01; Indian, Pakistani, Sri Lankan: 8.06; Other: 9.47; - SEP:; - ○ SEIFA IRSD (%): Quintile 1 (most disadvantaged): 16.75; Quintile 5: 17.85; - Baseline BMI: Median (IQR): 22.20 (20.87, 23.60); - Current HDP (%):; - ○ GHTN: ~1.4; - ○ PE/Eclampsia: ~2.5; - Current DM (%):; - ○ GDM: 12.4; - ○ T1 or T2 DM: 0.0; - Smoking (%): Smoker: 4.42 | LI vs SC; FFQ at: Trial entry (10-20 GW), 28 GW, and 36 GW; DP Description:; - LI: Received 3 in-person visits and 3 phone calls with dietitian or research assistant at trial entry, and 20, 24, 28, 32, and 36 GW. Dietary advice was consistent with current Australian dietary standards, maintaining a balance of carbohydrates, fat, and protein, and encouraging reduced intake of energy dense and non-core foods high in refined carbohydrates and saturated fats. Participants were advised to increase their intake of fibre, and to consume 2 svg/d fruit, 5 svg/d vegetables and 3 svg/d dairy.; - SC: Received antenatal care according to hospital guidelines, which did not include information relating to dietary intake, physical activity or weight gain during pregnancy.; Adherence: HEI scores from FFQ did not differ at baseline, but were higher in LI at 28 GW and 36 GW. Physical activity scores did not differ at either followup.; Outcomes:; - SGA: <10%ile according to local standards; - LGA: BW >90%ile; - LBW: <2500g; - Macrosomia: >4000g | SGA; Log binomial regression, OR (95% CI); [underlined: All]:; LA vs SC (Ref): 0.84 (0.48, 1.47), p=0.545; [underlined: Pre-pregnancy BMI], p-value for interaction=0.565; LA vs SC (Ref): 0.95 (0.48, 1.89), p=0.878; LGA; Log binomial regression; OR (95% CI); [underlined: All]:; LA vs SC (Ref): 0.88 (0.51, 1.52), p=0.641; [underlined: Pre-pregnancy BMI], p-value for interaction=0.200; LA vs SC (Ref) per 1 BMI unit:; 0.72 (0.38, 1.36), p=0.317; LBW; Log binomial regression, OR (95% CI); [underlined: All]:; LA: 1.32 vs SC (Ref): (0.69, 2.54), p=0.399; [underlined: Pre-pregnancy BMI], p-value for interaction=0.328; LA vs SC (Ref): 1.62 (0.74, 3.56), p=0.227; Macrosomia; Log binomial regression, RR (95% CI); [underlined: All]:; LA vs SC (Ref): 0.91 (0.54, 1.55), p=0.732; [underlined: Pre-pregnancy BMI], p-value for interaction=0.263; LA vs SC (Ref): 0.79 (0.44, 1.43), p=0.434 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Funding: The University of Adelaide; Lloyd Cox Strategic Research Excellence Award; NHMRC Practitioner Fellowship; Summary: Randomization to a dietitianled dietary and lifestyle intervention based on the Australian Guide to Healthy Eating, compared to standard antenatal care, did not affect risk of LGA, AGA, LBW, or BW >4.0 kg.
Gallagher, 2018^56^; RCT, United States, LIFT (Lifestyle; Intervention For Two); Analytic N=196 (Attrition: 7%); - Age (y): LI: 33.8±4.0; UC: 33.8±4.7; - Race/Ethnicity (%):; - ○ LI: Not Hispanic/Latina: 69; Hispanic: 30; White: 46; Other: 25; Black: 24; >1 Race: 5; Unknown: 1; - ○ UC: Not Hispanic/Latina: 76; Hispanic: 24; White: 48; Black: 24; Other: 21; >1 Race: 8; Unknown: 0; - SEP:; - ○ Education (%): ≤HS diploma: LI: 4.0; UC: 3.0; College degree: LI: 44; UC: 37; Postgraduate work: LI: 37; UC: 49; - ○ Annual family income (%): ≤24,999: LI: 3.0; UC: 7.0; 75k149k: LI: 36; UC: 33; ≥150k: LI: 29; UC: 32; - Pre-pregnancy BMI:; - ○ LI: 30.1±4.1, UC: 30.7±5.0; - ○ (%): 25-29.9: LI: 62, UC: 57; >30: LI: 38, UC: 43; - Current DM (%):; - ○ T1 or T2 DM: 0.0; - ○ GDM: LI: 10.3; UC: 6.1; - Smoking (%): 0.0 | LI vs UC; 24 HR at: 12-15.6, 36 GW; DP Description:; - LI: Diet modification and increased physical activity, along with behavioral and social support strategies delivered in individual sessions by study counselors. Focus was on GWG control as recommended by 2009 IOM guidelines.; - UC: A single 20-30 minute ‘Introduction’ immediately following randomization. Participants were invited to attend UC group meetings once every 8 wk through delivery; Adherence: No differences in HEI-2010 scores between groups at baseline. HEI-2010 was significantly higher in the LI group compared to the UC group at 36 GW. Between group change from baseline was also statistically significantly higher in the LI group compared to the UC group.; Outcomes:; - SGA: <10%ile according to local standards; - LGA: BW >90%ile | SGA; Chi-squared test, n (%); LI: 8 (8); UC: 13 (14); p=0.26; LGA; Chi-squared test, n (%); LI: 10 (10); UC: 6 (6); p=0.28 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Funding: NIH; NIDDK; NHLBI; NICHD; NCCIH; ORWH; OBSSR; The Indian Health Service; Summary: A GWG control intervention with higher alignment with HEI-2010 did not have an effect on risk of SGA or LGA when compared to a control group with lower alignment with HEI-2010.
Khoury, 2005^57^; RCT, Norway, CARRDIP (Cardiovascular Risk Reduction Diet in Pregnancy); Analytic N=290 (Attrition: 0%); - Age (y): ~29.7; Range: 21-38; - Race/Ethnicity (%): White: 100; - SEP: Education: ~82.1% >12 y; - Pre-pregnancy BMI: TM2: ~24.3±2.8; - Current HDP (%): Chronic HTN: 0.0; - Current DM (%): Pre-existing DM: 0.0; - Smoking (%): Nonsmokers: 100 (Previous smokers had to have quit ≥5y before inclusion) | IG vs CG; At: BL, 24 GW, 30 GW, and 36 GW; DP Description:; Women randomly allocated to usual or intervention diet and asked to follow assigned diet until delivery Intervention group received cooking lessons to implement special foods (e.g., legumes, olive oil); - IG: dietician encouraged intake of fatty fish, vegetable oils, especially olive oil and rapeseed oil, nuts, nut butters, margarine based on olive- or rapeseed oil, and avocado to replace meat, butter, cream, and fatty dairy products; ≥6/d fresh fruits and vegetables; intake of dairy products in the form of skimmed or low-fat products (skimmed milk, fat-reduced cheese, and yogurt) in place of full fat products; 2/wk meat for a main meal and legumes, vegetable main dishes, fatty fish, or poultry with the fat trimmed off on the other days; ≤2 cups/d coffee; - CG: subjects asked to consume their usual diet based on Norwegian foodstuffs, and not to introduce more oils or low-fat meat and dairy products than usual; Adherence: assessed by weighed dietary records:; - Intervention diet: included significantly more fish and fish products; fatty fish and fish products; rapeseedbased margarine; oils; olive oil; rapeseed oil; nuts, olives, and seeds; vegetables; and fruits, when compared to the control diet; - Control diet: included significantly more fatty milk, meat and meat products, fatty minced meat, butter, and hard margarines, when compared to the intervention diet; Outcomes:; - SGA: <10%ile | SGA; Fisher Exact Test; OR (95% CI); IG: 1.0 (0.4, 2.5); CG: Ref p=1.0 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Funding: The Norwegian Council on Cardiovascular Disease; Summary: There was no association between the experimental diets and SGA.
Melero, 2020^58^; Non-RCT, Spain, St. Carlos GDM prevention study; Analytic N=544 (Attrition: 9%); - Age (y): CG: 31.3±5.6, IG: 31.7±5.4; - Race/Ethnicity (%): Hispanic: 100; - SEP:; - ○ Education (%): Elementary: CG: 19.7, IG: 12.6; Secondary: CG: 47.2, IG: 46.2; University: CG: 31.7, IG: 40.6; Unknown: CG: 1.4, IG: 0.7; - ○ Unemployed (%): CG: 69.0, IG: 67.8; - Pre-pregnancy BMI: CG: 24.4±4.0, IG: 24.1±3.4; - Current HDP (%): CG: 4.9, IG: 2.8; - Current DM (%): CG: 34 (25.8), IG:19 (14.8); CG vs IG: p=0.021; - Smoking (%): CG: 0.7, IG: 0.7 | IG vs CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; The IG, CG, and real world group (RW) all given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg legumes/wk, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals.; - IG and RW also recommended to consume ≥40 mL/d of EVOO and nuts ≥3d/wk. IG was provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW. RW was not provided with EVOO or pistachios.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ between the groups at baseline. Scores significantly increased over time in the IG and RW, while no changes in the CG were observed. Scores remaining significantly higher in the IG and RW compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: vegetables; dishes with tomato sauce (tomato, garlic, onion, leek, olive oil); pulses; nuts; fish; white meat over red meat; olive oil; olive oil as principal cooking fat.; - Negative components: commercial pastries; red meat or sausages; animal fat; sugar-sweetened beverages; - Alcohol and fruit (including juice) component excluded; Outcomes:; - SGA: <10%ile by national charts; - LGA: >90%ile | SGA; Chi-square test; n (%); IG vs CG: 1 (0.8) vs 7 (5.3), p=0.036; LGA; Chi-square test; n (%); IG vs CG: 1 (0.8) vs 8 (6.1), p=0.020 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Greater alignment with a MedDiet supplemented with EVOO and pistachios in a trial (IG) reduced the risk of both SGA and LGA compared to lower alignment with a MedDiet in a trial setting (CG).
Van Horn, 2018^59^; RCT, United States, MOMFIT (Maternal Offspring Metabolics Family Intervention Trial); Analytic N=251 (Attrition: 11%); - Age (y): IG: 33±4; UC: 34±4; - Race/Ethnicity (%): White: IG: 56.4, UC: 70.2; Black or African American: IG: 24.3, UC: 14.2; Other: IG: 19.3; UC: 15.6; - SEP:; - ○ Total family income (%): <$20k: IG: 3.6, UC: 5.7; $20k−<$50k: IG: 12.4, UC: 13.5; $50k−<$75k: IG: 12.4, UC: 13.5; $75k−<$100k: IG: 13.9, UC: 9.9; $100k−<$150k: IG: 24.8, UC: 27.7; $150k−<$200k: IG: 16.8, UC: 10.6;≥$200k: IG: 16.1; UC: 19.2; - Pre-pregnancy BMI: IG: 31±4, UC: 31±4; - Current HDP (%): Family history of high blood pressure: IG: 67.9, UC: 75.2; - Current DM (%): 0% prior diagnosis of diabetes of HbA1c >6.5%; - Family history of diabetes: IG: 51.4, UC: 59.6; - Smoking (%): 0% | IG vs UC; 24 HR at: 15 GW, 36 GW; DP Description:; MAMA-DASH: Higher low-fat milk and dairy products, fish, skinless poultry, lean meat and vegetable protein, unsaturated fats, fiber-rich whole grains, fruits, vegetables, and legumes. Lower sugar-sweetened beverages, other sweets, and non-nutrient-dense snack foods was discouraged.; Caloric restriction to meet GWG, following nutrition guidelines for pregnant women, including avoidance of fish considered higher in mercury, inclusion of calcium-rich, vitamin D−enriched dairy, or calcium-fortified non-dairy products; Adherence: at 36 GW; Median (IQR); - Dixon DASH: Intervention group (IG): 4(3, 4); Usual care (UC): 3(3, 4), p=0.01; - Fung DASH: IG: 27(25, 30); UC: 26(22, 29), p=0.005; - HEI-2010: IG: 70(62, 77); UC: 63(56, 75), p=0.002; Outcomes:; - SGA: <10%ile; - LGA: >90%ile | SGA; IG: 25 (18.0), p=0.61; UC: 27 (19.9); LGA; Logistic regression model, n (%); IG: 8 (5.8), p=0.51; UC: 12 (8.8) | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Funding: NIDDK, NHLBI; NICHD; NCCIH; ORWH; OBSSR; the Indian Health Service; Summary: Randomization to DASH and physical activity coaching compared to usual care was not associated with SGA or LGA.
Zhao, 2022^60^; RCT, Parallel-arm, China, People’s Hospital of Zhengzhou University Baseline N=560; Analytic N= 500 (Attrition: 11%); - Age (y): CG: 28±5.2, IG: 29.4±5.6; - SEP:; - ○ Employed (%): CG: 75.2, IG: 46.4; - ○ Education (%) HS: CG: 10.0, IG: 10.8; University: CG: 37.2, IG: 38.8; Unknown: CG: 6.4, IG: 1.2; - Pre-pregnancy BMI: CG: 23.3±3.9, IG: 22.8±3.4; - Current DM (%): GDM: CG: 20.4, IG: 13.6, p=0.042; - Smoking (%): Current: CG: 2.4, IG: 2 | CG vs IG; FFQ at: 8-12 GW, 24-28 GW, 36-38 GW; DP Description:; - Both groups: MedDiet (vegetables, fruits, skimmed dairy foods, whole grain cereals, legumes, fish; avoid refined grains, baked goods, soft drinks, juices, junk food, precooked meat, pre-sliced slices of bread) and walking 30 min/d recommended; - IG: Recommended to consume ≥40 ml/d EVOO and 25-30 g/d roasted pistachios recommended; Weekly visits with a dietitian; - CG: Recommended to restrict dietary fat, including extra virgin coconut oil and dry fruits, by the midwives.; Adherence: MEDAS scores did not differ at baseline. Scores significantly increased over time in both groups, but the IG had significantly higher scores than the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries; Outcomes:; - SGA: <10%ile; - LGA: >90%ile | SGA; Chi-square; IG: 5.2, p=0.01; CG: 1.2; RR (95% CI); 0.23 (0.06, 0.79), p=0.020; LGA; Chi-square; IG: 3.6, p=0.03; CG: 0.8; RR (95% CI); 0.22 (0.04, 1.01), p=0.052 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, Pre-pregnancy BMI, Current HDP; Funding: No funding received; Summary: A MedDiet with recommended additional EVOO and pistachios lowers the risk of SGA and trended towards lowering risk of LGA.
NRCT
Melero, 2020^58^; Non-RCT, Spain, St. Carlos GDM prevention study; Analytic N=544 (Attrition: 9%); - Age (y): CG: 31.3±5.6, RW: 31.4±5.7; - Race/Ethnicity (%): Hispanic: 100; - SEP:; - ○ Education (%): Elementary: CG: 19.7, RW: 11.2; Secondary: CG: 47.2, RW: 50.8; University: CG: 31.7, RW: 35.5; Unknown: CG: 1.4, RW: 2.5; - ○ Unemployed (%): CG: 69.0, RW: 73.3; - Pre-pregnancy BMI: CG: 24.4±4.0, RW: 23.4±3.6; RW vs. CG, p=0.033; - Current HDP (%): CG: 4.9, RW: 2.5; - Current DM (%): CG: 34 (25.8); RW: 38 (13.4); RW vs CG: p=0.011; - Smoking (%): CG: 0.7, RW: 1.6 | RW vs CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; The IG, CG, and real world group (RW) all given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg legumes/wk, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals.; - IG and RW also recommended to consume ≥40 mL/d of EVOO and nuts ≥3d/wk. IG was provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW. RW was not provided with EVOO or pistachios.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ between the groups at baseline. Scores significantly increased over time in the IG and RW, while no changes in the CG were observed. Scores remaining significantly higher in the IG and RW compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: vegetables; dishes with tomato sauce (tomato, garlic, onion, leek, olive oil); pulses; nuts; fish; white meat over red meat; olive oil; olive oil as principal cooking fat.; - Negative components: commercial pastries; red meat or sausages; animal fat; sugar-sweetened beverages; Alcohol and fruit (including juice) component excluded; Outcomes:; - SGA: <10%ile by national charts; - LGA: >90%ile | SGA; Chi-square test; n (%); RW vs CG: 9 (3.2) vs 7 (5.3), p=0.307; LGA; Chi-square test; n (%); RW vs CG: 11 (3.9) vs 8 (6.1), p=0.457 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Greater alignment with a MedDiet supplemented with EVOO and pistachios in a real-world (RW) setting did not impact risk of SGA or LGA compared to CG.
Cohort Studies
Index/Score
Ancira-Moreno, 2020^50^; PCS, Mexico, PRINCESA (Pregnancy Research on Inflammation, Nutrition & City Environment: Systematic Analyses); Analytic N=660; - Age (y): 25.08±5.8; - SEP (%): Education ≤9 y: 56.0; - Pre-pregnancy BMI:; - ○ 25.72±5.2; - ○ (%): BMI ≥25 to <30: 32.5; ≥30 to <35: 12.4; ≥35: 5.0 | MDQS (Continuous alignment (per SD); Medium (3-4 pts), and high (≥5 pts) vs low (0-2 pts) alignment); 24HR at: TM2 and TM3; DP Description:; - Positive components: Fruits and vegetables (≥400 g per day), PUFA (≥6% of total energy), low fat dairy products (2 svg per day), legumes (2 svg per day); - Negative components: Red meat (≤500 g per wk), saturated fat and/or added sugars (<10% of energy).; Outcomes:; - LBW: <2,500 g | LBW; Logistic regression; OR (95% CI); Continuous (per SD): 0.53 (0.46, 0.82), p<0.001; Medium vs Low (Ref): 0.36 (0.17, 0.75), p=0.006; High vs Low (Ref): 0.22 (0.06, 0.75), p=0.016 | Key confounders accounted for: Parity, Age, SEP, Pre-pregnancy BMI Other covariates: Energy intake, GWG, maternal height, marital status, term of gestation, baby’s sex; Funding: NIEHS; Summary: Alignment with the MDQS was associated with lower risk of LBW.
Berube, 2023^3^; PCS, United States, StEP Trial (Starting Early Program Trial); Analytic N=498; - Age (y): 28±6; - Race/Ethnicity (%): Hispanic/Latina: 100; - SEP:; - ○ ≥HS education: 66.4; - ○ Employed: 24.8; - Pre-pregnancy BMI: 27.5±5.5 | HEI-2015 (tertiles of alignment); FFQ at: 28-32 GW; DP Description:; - Positive components: total fruits, whole fruits, total vegetables, greens and beans, whole grains, dairy, total protein, seafood and plant protein, fatty acids.; - Negative components: refined grains, sodium, saturated fat, added sugars.; Outcomes:; - SGA: ≤10%ile based on Fenton growth curves; - LGA: ≥90%ile | SGA; Logistic regression; OR (95% CI); T2 vs T1 (Ref): 0.8 (0.3, 1.8); T3 vs T1 (Ref): 0.6 (0.3, 1.6); LGA; Logistic regression; OR (95% CI); T2 vs T1 (Ref): 1.3 (0.6, 3.3); T3 vs T1 (Ref): 1.1 (0.4, 2.7) | Key confounders accounted for: Parity, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI; Other covariates: Marital status, physical activity, total energy; Funding: NIFA; NICHD; Summary: Alignment with Western DP, Fruits and vegetables DP, and the HEI-2015 was not associated with risk of SGA or LGA.
Chatzi, 2012^5^; PCS, Greece, Spain, INMA (Infancia y medio Ambiente), RHEA; Analytic N: INMA-Atlantic: 1,074; INMA-Mediterranean: 1,386; RHEA: 824; (INMA-Atlantic, INMA-Mediterranean, RHEA); - Age (y): ~31.5; ~30.2, p<0.001; ~29.5, p=0.006; - SEP:; - ○ Maternal education (%): ≤Primary: ~16, ~30.5, ~18.4; Secondary: ~38.3, ~43.7, ~51.2; University: ~45.7, ~25.8, ~30.4, p=0.003; - ○ Paternal education (%): ≤Primary: ~26.1, ~40.5, ~35.9; Secondary: ~49.5, ~41.4, ~42.4; University: ~24.5, ~18.1, ~21.7; - ○ Maternal social class (%): Professional-managerial: ~28, ~18.3; Skilled: ~23.7, ~27.0; Partly skilled, unskilled, or homemaker: ~48.2, ~54.7; - ○ Paternal social class (%): Professional-managerial: ~23.9, ~17.3; Skilled: ~14.6, ~19.4; Partly skilled, unskilled, or homemaker: ~61.5, ~63.3; - Pre-pregnancy BMI: ~23.5, ~23.7, ~24.3; - Current HDP (%): GHTN: ~2.1; ~2.4; ~3.1; - Current DM (%): DM before pregnancy: ~0.2, ~0.3, ~2.1; - Smoking (%): During pregnancy: ~15.9, ~19.5, p=0.049, ~23 | MD (High (6-8 pt); Medium (4-5 pt) vs Low (≤3 pt) alignment); FFQ at: INMA: ~13.8±2 GW; RHEA: 14-18 GW; DP Description:; [underlined: Mediterranean Diet (MD)]; - Positive components: vegetables, legumes, fruits and nuts, cereals, fish and seafood, dairy products, and the ratio of MUFA:SFA; - Negative components: all types of meat; Outcomes:; - SGA <10%ile | SGA; Multiple log-binomial regression; RR (95% CI); [underlined: INMA-Mediterranean]; Medium vs Low (Ref): 0.76 (0.54, 1.06); High vs Low (Ref): 0.50 (0.28, 0.90); [underlined: INMA-Atlantic]; Medium vs Low (Ref): 1.24 (0.81, 1.89); High vs Low (Ref): 0.97 (0.42, 2.26); [underlined: RHEA]; Medium vs Low (Ref): 1.82 (0.95, 3.49); High vs Low (Ref): 1.96 (0.90, 4.25) | Key confounders accounted for: Parity, Smoking, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: TEI; INMA-Atlantic: maternal social class; INMA-Mediterranean: maternal BMI and maternal social class; RHEA: paternal age and maternal education.; Funding:; INMA: Instituto de Salud Carlos III; the Conselleria de Sanitat Generalitat Valenciana; Universidad de Oviedo; Department of Health of the Basque Government; Provincial Government of Gipuzkoa; RHEA: Flight Attendant Medical Research Institute; EU Integrated Projects; HiWATE; Summary: Higher MD adherence in INMA-Mediterranean was associated with a lower risk of SGA. In the other 2 cohorts, there was no association between MD adherence and SGA.
Chen, 2021^6^; PCS, France, Ireland, Netherlands, Poland, United Kingdom, ALPHABET consortium: Lifeways, EDEN, ALSPAC (Avon Longitudinal Study of Parents and Children), SWS (Southampton Women’s Survey), REPRO_PL (Polish Mother and Child Cohort Study), Generation R; Analytic N=ALSPAC: 11,571; EDEN: 1,641; Generation R: 6,184; Lifeways: 832; REPRO_PL: 1,139; SWS: 1,851; - Age (y): 29.5 ± 4.9; - Race/Ethnicity (%): European-born/White: 89.9%; Non-Europeanborn/non-White: 10.1%; - SEP: Education level: Low: 16.9%, Medium: 51.6%, High: 31.5%; - Pre-pregnancy BMI: 23.3 ± 4.2; - Smoking (%):; - ○ Never: 57.7%; - ○ Ever: 23.0%; - ○ Current: 19.3% | DASH (continuous alignment, per 1 SD increase) FFQ at: First/early second trimester (5 cohorts); Third trimester (3 cohorts); DP Description:; - Positive components: fruits, vegetables excluding potatoes, total grains, non-full-fat dairy products, nuts/seeds/legumes.; - Negative components: red and processed meats, sugar-sweetened beverages/sweets/added sugars, sodium.; Outcomes:; - SGA <10%ile, based on INTERGROWTH-21st GA- and sex-specific reference growth curves | SGA; Logistic regression; OR (95% CI); [underlined: ALSPAC]: 0.93 (0.85, 1.02); [underlined: EDEN]: 0.88 (0.71, 1.09); [underlined: Generation R]: 0.78 (0.69, 0.88); [underlined: Lifeways]: 1.00 (0.68, 1.46); [underlined: REPRO_PL]: 0.94 (0.70, 1.27); [underlined: SWS]: 0.79 (0.61, 1.02) | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, SEP, Pre-pregnancy BMI Other covariates: maternal height, energy intake, alcohol consumption during pregnancy, child sex; Funding:; [underlined: ALSPAC]: UK Medical Research Council; Wellcome; University of Bristol; [underlined: EDEN]: Foundation for Medical Research; National Agency for Research; National Institute for Research in Public Health; French Ministry of Health; French Ministry of Research; INSERM Bone and Joint Diseases National Research and Human Nutrition National Research Programs; Paris-Sud University; Nestlé; French National Institute for Population Health Surveillance; French National Institute for Health Education; the EU FP7 programmes; Diabetes National Research Program; French Agency for Environmental Health Safety; Mutuelle Générale de l’Education Nationale; French national agency for food security; French-speaking association for the study of diabetes and metabolism; [underlined: Generation R]: Erasmus Medical Centre; Erasmus University Rotterdam; Netherlands Organization for Health Research and Development; EU Horizon 2020 Research and Innovation Programme; [underlined: Lifeways]: Irish Health Research Board; [underlined: REPRO_PL]: Ministry of Science and Higher Education Poland; Polish-Norwegian Research Fund; National Science Centre, Poland; [underlined: SWS]: Medical Research Council; British Heart Foundation; Arthritis Research UK; Food Standards Agency; EU Seventh Framework; Summary: Greater alignment with the DASH DP was associated with lower risk of SGA in 1 cohort (Generation R) but was not associated with risk of SGA in the remaining 5 cohorts.
Díaz-López, 2022^9^; PCS, Spain, ECLIPSES; Analytic N=614; - Age (y): 30.5±5.1; - Race/Ethnicity (%): NR for this sample, but from baseline of parent RCT: Maternal ethnic origin: Caucasian: 80.4; Latin American: 10.7; Arab: 6.3; Black: 2.0; Asian: 0.6; - SEP:; - ○ Social class, %, p=0.001: Low: T1: 20; T2: 22; T3: 10; Middle: T1: 67; T2: 54; T3: 65; High: T1: 13; T2: 24; T3: 25; - ○ Educational level, %, p=0.001: Primary or less: 33, 33, 27; Secondary: 44, 35, 30; University: 23, 32, 43; - Pre-pregnancy BMI:; - ○ 25.1±4.5; - ○ (%): BMI <25: 58; BMI ≥25: 42; - Smoking (%): No: 83; Yes: 17 | Relative MedDiet (tertiles of adherence); FFQ at: 12, 24, 36 GW; DP Description:; - Positive components: fruits, vegetables, legumes, cereals, fresh fish and olive oil; - Negative components: meat, dairy, alcohol; Outcomes:; - SGA: <10%ile according to INTERGROWTH-21st GA- and sex-specific reference growth curves. | SGA; Multivariable logistic regression; OR (95% CI); T3 vs T1 (Ref): 0.36 (0.16, 0.79), p<0.05; T2 vs T1 (Ref): 0.42 (0.22, 0.81), p<0.05 p-trend=0.005; Multivariable logistic regression; OR (95% CI), per 1 pt increase; 0.74 (0.64, 0.85), p<0.05; No change in the results after excluding newborns with GA <37 GW (data NR). | Key confounders accounted for: Parity, Smoking, Age, SEP, Pre-pregnancy BMI; Other covariates: PA, planned pregnancy, energy intake; Funding: Health Research Fund of the Ministry of Health and Consumption; European Union; Summary: Higher alignment with a relative MedDiet was associated with lower risk of SGA.
Emond, 2018^10^; PCS, United States, New Hampshire Birth Cohort Study; Analytic N=862 (nonsmokers: n=756); AHEI-2010 Q1, Q4; - Age (y): 28.9±5.0, 33.2±4.4, p<0.001; - Race/Ethnicity (%): NHW: 94.9, 98.2; - SEP: Education, p<0.001: ≤HS graduate: 41.9, 15.3; Some college: 23.3, 23.2; ≥College graduate: 34.9, 61.6; - Pre-pregnancy BMI (%): p=0.05: 18.5-24.9: 46.5, 58.3; 25.0-29.9: 27.4, 27.8; ≥30: 26.1, 13.9; - Current HDP (%): Preeclampsia: 1.9, 2.8; - Current DM (%):; - ○ Any past DM: 7.0, 4.2; - ○ GDM: 5.6, 7.5; - Smoking (%): p<0.001; - ○ Nonsmoker: 79.5, 93.5; - ○ Former smoker: 8.8, 4.6; - ○ Smoker: 11.6, 1.9 | AHEI-2010 (quartiles of alignment); FFQ at: 24-28 GW; DP Description:; - Positive components: fruits, vegetables, whole grains, nuts and legumes, long-chain omega-3 fatty acids (EPA+DHA), PUFA; - Negative components: sugary beverages, red and processed meats, trans fatty acids, sodium.; - Modified to exclude moderate alcohol component.; Outcomes:; - SGA: <10%ile based on age- and sex-adjusted Fenton growth curves; - Macrosomia: >4000 g; - LGA: >90%ile based on age- and sex-adjusted Fenton growth curves; - LBW: <2500 g | SGA; Logistic regression; OR (95% CI); [underlined: Overall]; Q2 vs Q1 (Ref): 0.89 (0.37, 2.15); Q3 vs Q1 (Ref): 0.73 (0.28, 1.89); Q4 vs Q1 (Ref): 0.35 (0.11, 1.08); p trend: 0.03 [underlined: Nonsmokers]; Q2 vs Q1 (Ref): 0.78 (0.28, 2.14); Q3 vs Q1 (Ref): 0.78 (0.27, 2.27); Q4 vs Q1 (Ref): 0.44 (0.13, 1.47); p trend: 0.04; LGA; Logistic regression; OR (95% CI); [underlined: Overall]; Q2 vs Q1 (Ref): 1.20 (0.62, 2.33); Q3 vs Q1 (Ref): 0.86 (0.42, 1.79); Q4 vs Q1 (Ref): 0.71 (0.32, 1.57); p trend: 0.28; [underlined: Nonsmokers]; Q2 vs Q1 (Ref): 1.24 (0.62, 2.49); Q3 vs Q1 (Ref): 0.79 (0.36, 1.70); Q4 vs Q1 (Ref): 0.60 (0.26, 1.38); p trend: 0.25; LBW; Logistic regression; OR (95% CI); [underlined: Overall]; Q2 vs Q1 (Ref): 1.15 (0.38, 3.49); Q3 vs Q1 (Ref): 0.54 (0.14, 2.11); Q4 vs Q1 (Ref): 1.20 (0.34, 4.24); p trend: 0.95; [underlined: Nonsmokers]; Q2 vs Q1 (Ref): 1.14 (0.35, 3.73); Q3 vs Q1 (Ref): 0.79 (0.2, 3.22); Q4 vs Q1 (Ref): 1.27 (0.32, 4.97); p trend: 0.66; Macrosomia; Logistic regression; OR (95% CI); [underlined: Overall]; Q2 vs Q1 (Ref): 0.79 (0.43, 1.46); Q3 vs Q1 (Ref): 0.88 (0.48, 1.63); Q4 vs Q1 (Ref): 0.76 (0.39, 1.46); p trend: 0.21 [underlined: Nonsmokers]; Q2 vs Q1 (Ref): 0.78 (0.41, 1.48); Q3 vs Q1 (Ref): 0.67 (0.34, 1.30); Q4 vs Q1 (Ref): 0.65 (0.32, 1.29); p trend: 0.07 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: infant sex, GWG, PA during pregnancy, maternal urinary arsenic, total daily caloric intake; Funding: NIEHS; NIGMS; Environmental Protection Agency; Summary: Greater alignment with the AHEI-2010 was associated with lower risk of SGA. Greater alignment trended toward lower risk of macrosomia among nonsmokers but did not reach statistical significance. Alignment with the AHEI-2010 was not associated with LBW or LGA.
Fulay, 2018^13^; PCS, United States, Project Viva; Analytic N=1743; - Age (y): 32.2±4.9; - Race/Ethnicity (%): White: 71.9; Black: 12.3; Hispanic: 6.5; Asian: 5.6; Other: 3.6; - SEP:; - ○ Household income (%): <$20k/y: 3.1; >$70k/y: 60.1; - ○ Education (%): Primary: 9.4; ≥College: 32.0; - Pre-pregnancy BMI: 25-<30: 21.7; ≥30: 12.9; - Current HDP (%): HDP: 10.7; - Current DM (%):; - ○ Current GDM: 5.2; - ○ Current T1 or T2 DM: 0.0; - Smoking (%): 10.9 | DASH & DASH OMNI (continuous alignment); FFQ at: ~11 GW; DP Description:; [underlined: DASH]; - Positive components: fruits; vegetables; whole grains; nuts/legumes; low-fat dairy; - Negative components: sodium; SSB; red and/or processed meats; [underlined: DASH OMNI]; - Positive components: fruits; vegetables; whole grains; nuts/legumes; low-fat dairy; MUFA and PUFA; - Negative components: sodium; SSB; red and/or processed meats; Outcomes:; - SGA: BW <10%ile, by GA- and sex-specific Oken reference; - LGA: BW ≥90%ile; - AGA: BW 10-90%ile | SGA vs. AGA; Logistic regression; OR (95% CI); [underlined: DASH]: 0.97 (0.93, 1.02), p≥0.05; [underlined: DASH OMNI]: 0.97 (0.93, 1.02), p≥0.05; Additionally adjusting for Western and Prudent DP did not substantially alter the results; LGA vs. AGA; Logistic regression; OR (95% CI); [underlined: DASH]: 0.99 (0.96, 1.02), p≥0.05; [underlined: DASH OMNI]: 0.99 (0.96, 1.02), p≥0.05; Additionally adjusting for Western and Prudent DP; [underlined: DASH]: 0.94 (0.90, 0.99), p<0.05; [underlined: DASH OMNI]: 0.94 (0.89, 0.99), p<0.05 | Key confounders accounted for: Parity, magnitude, or precision of the results, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: GWG until FFQ; TEI; Funding: NIH; Summary: Alignment with DASH or DASH OMNI was not associated with SGA or LGA when not adjusting for Western or Prudent DP. When additionally adjusting for these DP, greater alignment with DASH and DASH OMNI was associated with reduced risk of LGA, but not risk of SGA.
Gonzalez-Nahm, 2019^14^; PCS, United States, Nurture; Analytic N=817; - Age (y): 27.4±5.8; - Race/Ethnicity (%): Black: 70.2; White: 20.9; Other: 8.9; - SEP:; - ○ Household income (%): <$20k: 58.9; $20k-40k: 22.4; >$70k: 8.0; - ○ Education (%): ≤HS graduate: 45.2; Some college/college or higher: 54.8; - Pre-pregnancy BMI: 30.1±9.3; - Current HDP (%): NR; - Current DM (%): NR; - Smoking (%): 14.8 | AHEI-2010 (continuous alignment); FFQ at: 20-36 GW; DP Description:; - Positive components: vegetables, fruit, whole grains, nuts and legumes, long-chain omega-3 fatty acids (DHA and DPA), PUFA; - Negative components: SSBs, red/processed meat, trans fat, sodium; - Modified to exclude alcohol component; Outcomes:; - SGA: BW <10%ile, based on INTERGROWTH-21st reference growth curves; - LGA: BW >90%ile; - LBW: BW <2500 g; - Macrosomia: BW >4000 g | SGA; Logistic regression; OR (95% CI); 0.98 (0.94, 1.01), p=0.16; LGA; Logistic regression; OR (95% CI); 1.02 (0.98, 1.05), p=0.33; LBW; Logistic regression; OR (95% CI); 0.99 (0.95, 1.03), p=0.60; Macrosomia; Logistic regression; OR (95% CI); 1.04 (0.98, 1.90), p=0.07; Similar results in analyses restricted to Black women and infants or excluding PTB | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI; Other covariates: daily kcal intake; infant sex; Funding: NIH; Summary: Alignment with the AHEI2010 was not associated with risk of SGA, LGA, LBW, or macrosomia.
Hillesund, 2014^17^; PCS, Norway, MoBa (Norwegian Mother and Child Cohort Study); Exposure N=High: 25,237; Medium: 23,558, Comparator N=17,802; - Age (y):; - ○ 30.1±4.6, p<0.001; - ○ (%) ≤19: 0.9; 20-34: 82.2; ≥35: 16.9, p<0.001; - SEP: Education (%): 31.2; 13-16: 42.7; ≥17: 26.2, p<0.001; - Pre-pregnancy BMI:; - ○ 24.0±4.2, p<0.001; - ○ (%): <25: 69.2; 25–29: 21.6; ≥30: 9.3, p<0.001; - Current DM (%): Pre-existing DM: 0.0; - Smoking Yes: 7.8, p<0.001 | NND High (score: 6-10) or Medium (score: 4-5) vs Low (score: 0-3) alignment; FFQ at: ~22 GW; DP Description:; New Nordic Diet (NND); Positive components: (i) eating ≥24 main meals/wk; (ii) eating Nordic fruits ≥5 times/week; (iii) eating root vegetables ≥5 times/week; (iv) eating cabbage ≥2 times/week; (v) eating potatoes ≥one-third of total occasions of eating potatoes, rice or pasta; (vi) choosing whole grain bread more often than refined bread; (vii) eating oatmeal ≥monthly; (viii) eating fish/game/berries about 2 times/week; (ix) drinking milk more often than juice; and (x) drinking ≥6 times as much water as sugar-sweetened beverages; Outcomes:; - SGA: <10%ile, by “gender-specific” reference from MoBa cohort; - LGA: >90%ile | SGA vs AGA; Multinomial logistic regression; OR (95% CI); Medium vs Low (Ref): 0.95 (0.89, 1.02); High vs Low (Ref): 0.92 (0.86, 0.99); LGA vs AGA; Multinomial logistic regression; OR (95% CI); Medium vs Low (Ref): 1.04 (0.97, 1.12); High vs Low (Ref): 1.07 (1.00, 1.15) | Key confounders accounted for: Parity, Smoking, Age, SEP, Pre- pregnancy BMI, DM in current pregnancy; Other covariates: maternal height, exercise, energy intake; Funding: Norwegian Ministry of Health and the Ministry of Education and Research; NIH; the Norwegian Research Council/FUGE; University of Agder.; Summary: High alignment with the NND, compared to low alignment, was associated with lower odds of SGA and greater odds LGA. Medium alignment with the NND was not statistically significantly associated with SGA or LGA but trended in the same direction as high alignment.
Hillesund, 2018^18^; PCS, Norway, NFFD (Norwegian Fit for Delivery); Analytic N=587; - Age (y): 28.0±4.4; - ○ (%): ≥35: 6.8; - Race/Ethnicity (%): “Predominantly White”; - SEP:; - ○ Education (%): ≤12y: 31.8; ≥16y: 35.5; - ○ Occupation (%): Work outside home: 84.2; Student: 8.7; Unemployed: 3.9; Sick leave/disabled: 1.9; Homemaker: 1.4; - ○ Income (%): ≤400k NOK: 31.2; >700k NOK: 34.4; NR: 6.6; - Pre-pregnancy BMI: (%) 25-29.9: 20.2; ≥30: 7.6; - Current HDP (%):; - ○ PE: 4.3; - ○ Severe PE: 2.6; - Current DM (%):; - ○ Pre-existing DM: 0.0; - ○ GDM: 9.1; - Smoking (%): 3.9 | NFFD diet (continuous alignment); FFQ at: ~15 GW; DP Description:; - Positive components: regular meals; drinking water when thirsty; vegetables w/ dinner; fruits and vegetables between meals; reading nutrition labels before buying; - Negative components: sweets and snacks without appreciation; large portion sizes of unhealthy foods; added sugar; salt; eating beyond satiety; Outcomes:; - SGA: BW <10%ile based on sex- and GA-specific references from Medical Birth Registry of Norway; - LGA: BW ≥90%ile; - LBW: BW <2,500 g; - Macrosomia: BW ≥4,000 g and ≥4,500 g | SGA; Multivariate logistic regression; OR (95% CI); 1.13 (0.98, 1.29), p=0.089; Additionally adjusted for PA: 1.10; (0.94, 1.28), p=0.225; LGA; Multivariate logistic regression; OR (95% CI); 0.79 (0.62, 1.01), p=0.062; Additionally adjusted for PA: 0.80; (0.60, 1.09), p=0.166; LBW (n=552); Multivariate logistic regression; OR (95% CI); 1.25 (0.84, 1.86), p=0.267; Additionally adjusted for PA: 1.20; (0.79, 1.83), p=0.387; Macrosomia (n=552); Multivariate logistic regression; OR (95% CI); [underlined: BW >4,000 g]; 0.89 (0.78, 1.01), p=0.061; Additionally adjusted for PA: 0.91; (0.79, 1.05), p=0.185; [underlined: BW >4,500 g]; 0.54 (0.35, 0.84), p=0.006; Additionally adjusted for PA: 0.60; (0.33, 1.10), p=0.097; Sensitivity analysis confined to the control group in the original trial did not materially impact the results | Key confounders accounted for: Parity, Smoking, Age, SEP, Prepregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: Marital status; Randomization assignment; Funding: South-Eastern Norway Regional Health Authority; The municipalities of southern Norway; The University of Agder; Summary: Greater alignment with the NFFD diet was associated with reduced risk of BW >4,500 g and the association trended toward statistical significance for reduced risk of BW >4,000 g and LGA. Statistical significance of the associations was attenuated when additionally adjusting for physical activity. Alignment with the NFFD diet was not associated with risk of SGA or LBW.
Hrolfsdottir, 2019^19^; PCS, Iceland, PREWICE (PREgnant Women of ICEland); Exposure N=1651; Medium scores: n=766, High scores: n=508, Comparator N=Low scores: n=377; - Age (y): 30.2±5.2; - SEP: Education (%): Elementary schooling: 13, HS and technical school: 29, University: 35, Higher academic: 24; - Pre-pregnancy BMI:; - ○ Median (IQR): 24.1 (6.5); - ○ (%) BMI ≥25: 24, BMI ≥30: 18; - Smoking (%): Before pregnancy: 16, During pregnancy: 7 | Dietary risk score (low scores ≤2, medium scores 3, high scores ≥4; continuous); FFQ at: 11-14 GW; DP Description:; [underlined: Dietary risk score based on Icelandic Food-Based] [underlined: Dietary Recommendations and Nordic Nutrition] [underlined: Recommendations]; - Negative components: Not eating a varied diet (excluded/avoided any of the main food groups: cereal, vegetables/fruits, fish, meat, eggs, high-fat foods, or dairy), fruits/vegetables <5/d, dairy <2/d, whole grain products <2/d, sugar/artificially sweetened beverages ≥5/d, dairy ≥5/d; Outcomes:; - Macrosomia: >4500 g | Macrosomia; Logistic regression; OR (95% CI); Medium vs Low (Ref): 1.39 (0.73, 2.62); High vs Low (Ref): 2.20 (1.14, 4.25); Continuous: 1.41 (1.09, 1.83); Continuous, stratified by prepregnancy BMI; [underlined: <25]: 1.62 (1.10, 2.40); [underlined: 25-30]: 1.53 (0.95, 2.48); U: 0.82 (0.43, 1.56); Dietary risk score by BMI interaction: p=0.03 | Key confounders accounted for: Parity, Smoking, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: total gestational length, offspring sex; Funding: University of Iceland Research Fund; The Technology Development Fund/The Icelandic Centre for Research; Summary: Alignment with a dietary risk score was associated with higher risk of macrosomia. This association varied by prepregnancy BMI (dietary risk score among participants with BMI <25 was associated with higher risk of macrosomia).
Lipsky, 2023^24^; PCS, United States, PEAS (Pregnancy Eating Attributes Study); Analytic N=313; - Age (y): 30.6±4.5; - ○ Race/Ethnicity (%): NHW: 71; NHB or NH African American: 17; Hispanic or Latino: 7; NH Asian: 5; NH American Indian/Alaska Native: 0.3; NH Native Hawaiian/Pacific Islander: 0.3; Other race: 0.3; - SEP:; - ○ Education (%): ≥Bachelor’s degree: 73, ≤bachelor’s degree: 27; - ○ Employment (%): Full-time: 63, Part-time: 15, Student: 5, Not working: 17; - ○ Income-poverty ratio: 3.9±2.0; - Pre-pregnancy BMI (%):; - ○ Overweight: 27; - ○ Obesity: 24; - Current DM (%):; - ○ Preexisting DM: 0.0; - ○ GDM: 7.2 | HEI-2015 (continuous, per 1 point increase); 24 HR at: ≤15 GW, 16-27 GW, 28-36 GW; DP Description:; Positive components: total fruit, whole fruit, total vegetables, greens and beans, whole grains, dairy, total protein, seafood and plant proteins, fatty acids. Negative components: refined grains, sodium, added sugars, saturated fats.; Outcomes:; - LGA: >90%ile, per American College of Obstetricians and Gynecologists recommendations | LGA; Logistic regression; OR (95% CI); [underlined: HEI-2015 total score]: 0.95 (0.92, 0.98), p=0.003; [underlined: HEI-2015 adequacy score]; (positive components): 0.95 (0.91, 0.998), p=0.04; [underlined: HEI-2015 moderation score]; (negative components): 0.86; (0.79, 0.94), p<0.001 | Key confounders accounted for:; Age, SEP, DM in current pregnancy; Other covariates: None; Funding: NICHD; Summary: Alignment with the HEI-2015 was associated with lower risk of LGA
Makarem, 2022^26^; PCS, United States, nuMoM2b (Nulliparous Pregnancy Outcomes Study: Monitoring Mothers-to-Be); Analytic N =7,798; - Age (y): 27.4±5.5; - ○ (%): ≥35: 9.7; - Race/Ethnicity (%): NHW: 63.9; Hispanic: 16.6; NHB: 10.5; Asian: 4.3; Other: 4.6; - SEP:; - ○ Education (%): <HS: 5.7; ≥Bachelor’s: 55.6; - Baseline BMI ≥30 (%): 19.5; - Current HDP (%):; - ○ Chronic HTN: 0.0; - ○ GHTN: ~14%; - Current DM (%): 3.8; - Smoking (%): Ever: 41.4 | aMED (categorical alignment, quintiles of alignment) FFQ at: 6-<14 GW; DP Description:; - Positive components: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA:SFA; - Moderate component: Alcohol; - Negative component: Red and Processed Meat Outcomes:; - SGA: <5%ile by Alexander criteria | SGA; Multivariable logistic regression; OR (95% CI); Moderate vs. Low (Ref): 1.00 (0.81, 1.23) p=0.99; High vs. Low (Ref): 1.03 (0.81, 1.31) p=0.79; Quintile 2 vs. Quintile 1 (Ref): 1.03 (0.83, 1.29) p=0.77; Quintile 3 vs. Quintile 1 (Ref): 0.84 (0.61, 1.13) p=0.25; Quintile 4 vs. Quintile 1 (Ref): 1.20 (0.89, 1.61) p=0.23; Quintile 5 vs. Quintile 1 (Ref): 0.81 (0.58, 1.11) p=0.19; p for trend=0.07 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI; Other covariates: Marital status; Family history of CVD; Funding: NIH/ORWH BIRCWH; NIH/NHLBI; NIH/NICHD; OBSSR; NCATS; NIH/NIA; the Barbra Streisand Women’s Cardiovascular Research and Education Program; the Erika J. Glazer Women’s Heart Research Initiative; AHA; NIH/NINDS; the Gerstner Family Foundation; Summary: Alignment with aMed was not associated with risk of SGA.
Navarro, 2019^31^; PCS, Ireland, Lifeways CrossGeneration Cohort Study; Analytic N=958; - Age (y): 30.1 ± 5.9; - SEP:; - ○ Education (%): <Tertiary: 51, ≥Tertiary: 49; - ○ Household income (£/wk, %): <200: 14, >600£: 36; - Pre-pregnancy BMI: 23.8 ± 4.2; - Smoking (%): During pregnancy: 25 | HEI-2015 (tertiles of alignment; per 10pt increase); FFQ at: 12-16 GW; DP Description:; - Positive components: total fruits, whole fruits, total vegetables, greens and beans, total protein containing foods, seafood and plant proteins, whole grains, dairy, ratio of PUFAs and MUFAs to SFAs; - Negative components: refined grains, sodium, added sugars, saturated fats; Outcomes:; - LBW: <2500 g; - Macrosomia: >4000 g | LBW; Logistic regression; OR (95% CI); T2 vs T1 (Ref): 0.82 (0.37, 1.82); T3 vs T1 (Ref): 0.53 (0.19, 1.02); p trend: 0.04; Continuous (per 10-point increment): 0.72 (0.50, 0.99), p<0.05; Macrosomia; Logistic regression; OR (95% CI); T2 vs T1 (Ref): 1.15 (0.73, 1.76); T3 vs T1 (Ref): 1.21 (0.54, 1.74); p trend: 0.45; Continuous (per 10-point increment): 1.02 (0.89, 1.14) | Key confounders accounted for: Parity, Smoking, Age, SEP, household income, Pre-pregnancy BMI; Other covariates: marital status, alcohol consumption, energy intake, sex; Funding: Irish Health Research Board; Summary: Greater alignment with HEI-2015 was associated with lower risk of LBW. Alignment with HEI-2015 was not associated with risk of macrosomia.
Navarro, 2020^30^; PCS, Ireland, Lifeways CrossGeneration Cohort Study; Analytic N=1,072; - Age (y): ~31, p=0.02; - SEP:; - ○ Higher (≥tertiary) education level (%): ~53, p=0.001; - ○ Household weekly income, >600£ (%): ~34, p<0.001; - Pre-pregnancy BMI: ~23.8, p<0.001; - Smoking (%): Never or former smoker: ~79, p<0.001 | HEI-2015 (top 40%ile vs < top 40%ile); FFQ at: 12-16 GW; DP Description:; - Positive components: total fruit, whole fruit, total vegetables, greens and beans, whole grains, dairy, total protein, seafood and plant proteins, fatty acids.; - Negative components: refined grains, sodium, added sugars, saturated fats.; Outcomes:; - LBW: <2500g; - Macrosomia: >4000g | LBW; Logistic regression; OR (95% CI); <top 40%ile vs top 40%ile (Ref):; 1.61 (1.01, 7.85), p=0.04; Macrosomia; Logistic regression; OR (95% CI); <top 40%ile vs top 40%ile (Ref):; 0.61 (0.17, 2.09) | Key confounders accounted for: Smoking, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: marital status, child sex, BMI, PA, alcohol intake; Funding: Irish Health Research Board; Summary: Alignment with HEI-2015 was associated with lower risk of LBW. Alignment with HEI-2015 was not associated with risk of macrosomia.
Okubo, 2023^33^; PCS, Japan, Japan Environment; and Children’s Study; Analytic N=72,317; - Age (y): 31.4±5.0; - SEP: Educational attainment (%): <13 y: 35.3, ≥15 y: 22.1; - Pre-pregnancy BMI: 21.2±3.3; - Smoking (%): Never: 59.2, Ex-smoker (quit before becoming pregnant): 36.3, Smoker during early pregnancy: 4.5 | Balanced diet score (quartiles of alignment; continuous per 10-point increase) FFQ at: TM1 and TM2; DP Description:; - Positive components: Grain dishes, vegetable dishes, fish and meat dishes, milk, fruits.; - Negative components: snacks and alcoholic beverages, sodium from seasonings; Outcomes:; - LBW: <2,500 g | LBW; Bayesian logistic regression; OR (95% CI); Q2 vs Q1 (Ref): 0.96 (0.87, 1.04); Q3 vs Q1 (Ref): 0.91 (0.83, 1.00); Q4 vs Q1 (Ref): 0.87 (0.79, 0.96); Per 10-point increase: 0.92 (0.88, 0.96) | Key confounders accounted for: Parity, Smoking, Age, SEP, Pre-pregnancy BMI; Other covariates: height, GWG, GA at birth, alcohol drinking habit, routine use of a folic acid supplement, physical activity, infant sex; Funding: Ministry of the Environment, Japan; Summary: Higher alignment with a balanced diet score was associated with a lower risk of LBW.
Parisi, 2020^35^; PCS, Italy, Luigi Sacco University Hospital; Analytic N=94; - Age (Median (range), y): 31 (18-43); - SEP: Employed (%): 75; - Pre-pregnancy BMI (Median (range): 21.9 (15.6-39.5); - Current HDP (%): 3.2; - Current DM (%): GDM: 11.7; - Smoking (%): Periconceptional: 11.6 | FIGO Recommendations (<5 vs ≥5); Questionnaire at: 11-13 GW; DP Description:; - Positive components: Meat, fruit and vegetables, fish, dairy products, whole cereals, hemoglobin concentration, folic acid supplementation, iodized salt, sun exposure.; - Negative components: Sweets and snacks.; Outcomes:; - SGA: ≤10%ile; - LGA: ≥90%ile | SGA; RR; <5 vs ≥5: Data NR, p>0.05; LGA; RR; <5 vs ≥5: Data NR, p>0.05 | Key confounders accounted for: Parity, Smoking, Age, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: GA at enrollment, fetal sex; Funding: None; Summary: Alignment with FIGO recommendations was not associated with SGA or LGA.
Poon, 2013^36^; PCS, United States, IFPS II (Infant Feeding Practices Study II); Analytic N=755 (SGA), 775 (LGA); - Age (y): 29.1±5.4, p<0.001; - Race/Ethnicity (%): White: 87.4; - SEP:; - ○ Education (%): ≤HS: 18.0; Some College: 39.3; Associate or BA: 31.7; ≥Master: 10.9, p<0.001; - ○ Poverty index ratio (%): <185%: 37.5; 185 to 350%: 38.8; ≥350%: 23.7, p<0.0001; - Pre-pregnancy BMI: 26.1±6.4, p<0.0001; - Current DM (%):; - ○ T1 or T2 DM: 0.0; - ○ GDM: n=46; - Smoking (%): 8.3 | AHEI-P; aMed (tertiles of alignment); FFQ at: 28-36 GW; DP Description:; [underlined: AHEI-P]; - Positive components: vegetables, whole fruit, whole grains, nuts and legumes, long-chain omega-3 fats (EPA+DHA), PUFA, calcium, folate, iron.; - Negative components: SSB, red/processed meat, trans fat, sodium.; [underlined: aMed]; - Positive components: vegetables, legumes, fruits, nuts, whole grains, fish, MUFA:SFA; - Negative component: red and processed meat; Outcomes:; - SGA: ≤10%ile, sex- and GA-specific Canadian growth reference; - LGA: ≥90%ile | SGA; Poisson regression; RR (95% CI); [underlined: AHEI-P]; T2 vs T1 (Ref): 0.73 (0.41, 1.31); T3 vs T1 (Ref): 0.93 (0.49, 1.75); [underlined: aMed]; T2 vs T1 (Ref): 0.75 (0.44, 1.29); T3 vs T1 (Ref): 0.94 (0.48, 1.81); LGA; Poisson regression; RR (95% CI); [underlined: AHEI-P]; T2 vs T1 (Ref): 0.74 (0.43, 1.26); T3 vs T1 (Ref): 0.92 (0.50, 1.69); [underlined: aMed]; T2 vs T1 (Ref): 0.71 (0.44, 1.14); T3 vs T1 (Ref): 0.71 (0.37, 1.35) | Key confounders accounted for: Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: TEI, alcohol consumption during pregnancy; Funding: Eunice Kennedy Shriver NICHD; FDA; CDC; Office of Women’s Health, NIH; Maternal and Child Health Bureau, HHS; Summary: Alignment with the AHEI-P or aMED was not associated with risk of SGA or LGA.
Reyes-López, 2021^37^; PCS, Mexico, OBESO (Origen bioquímico y epigenético del sobrepeso y la obesidad); Analytic N=211; - Age (y): 28.8±8.1; - ○ ≥19y: 84.5%; - SEP (%):; - ○ Occupation: Homemaker: 66.4; Employed: 23.9; Students: 9.7%; - ○ Educational level: High: 65.2; Medium: 28.5; Low: 6.3; - Pre-pregnancy BMI: 26.1±5.2; - ○ Overweight: 32.7%; - ○ Obesity: 20.8%; - Current HDP: No HDP; - Current DM: No DM | AHEI-10P (continuous alignment; per 5-unit increase); 24 HR averaged across: 20-24 GW, 24.1-28 GW, 28.1-34 GW, ≥34 GW; DP Description:; - Positive components: vegetables, fruit, whole grains, nuts and legumes, fish, PUFA, calcium, iron, folate.; - Negative components: SSBs and fruit juice, red/processed meat, trans fat.; Outcomes:; - SGA: Cut-off not defined; - LBW: Cut-off in g NR | SGA; [underlined: Overall Sample]; Multiple logistic regression; β, OR (95% CI); −0.63, 0.52 (0.34, 0.82), p=0.00; Note: p<0.05 for interaction of diet quality and energy intake; [underlined: Women without PE or GDM]; (n=190); Multiple logistic regression; β, OR (95% CI); −0.96, 0.38 (0.22, 0.64), p=0.00; Note: p<0.05 for interaction of diet quality and energy intake; LBW; [underlined: Overall Sample] (excludes PTB); Multiple logistic regression; β, OR (95% CI); −0.79, 0.45 (0.25, 0.79), p=0.00; Note: p<0.05 for interaction of diet quality and energy intake; [underlined: Women without PE or GDM]; (excludes PTB, n=NR); Multiple logistic regression; β, OR (95% CI); −0.82, 0.44 (0.24, 0.79), p=0.00; Note: p<0.05 for interaction of diet quality and energy intake | Key confounders accounted for: Parity, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: TEI, interaction of diet quality and energy intake, GWG, sex, multivitamin use; Funding: Instituto Nacional de Perinatología; FOSISS-CONACyT; Summary: Higher alignment with AHEI-10P was associated with lower risk of LBW and SGA.
Rifas-Shiman, 2009^38^; PCS, United States, Project Viva; Analytic N=TM1: 1,777; TM2: 1,666; - Age (y): 32.4±4.9; - Race/Ethnicity (%): White: 72; Other, ≥1 race: 16; Black/African American: 12; - SEP (%):; - ○ Education: ≤HS diploma: 9; College graduate: 69; - ○ Household income <$40K: 13; - Pre-pregnancy BMI: (%): 25-29.9: 21; ≥30: 14; - Current HDP (%): PE: 3.4; - Current DM (%): GDM: 5 | AHEI-P (continuous; per 5 pt score increase); FFQ at: TM1 (11.7±3.1 GW), TM2 (26-28 GW); DP Description:; AHEI-P; - Positive components: vegetables, fruit, ratio of white to red meat, fiber, ratio of PUFA to SFA, and folate, calcium, and iron from foods; - Negative component: trans fat Outcomes:; - SGA: <10th%ile, by GA- and sex-specific Oken reference; - LGA: >90%ile | SGA vs AGA:; Multinomial Logistic Regression; OR (95% CI); TM1: 0.92 (0.82, 1.02); TM2: 1.00 (0.90, 1.10); LGA vs AGA; Multinomial Logistic Regression; OR (95% CI); TM1: 0.95 (0.89, 1.02); TM2: 0.99 (0.92, 1.07) | Key confounders accounted for: Parity, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: None; Funding: NIH; Harvard Medical School; Harvard Pilgrim Health Care Foundation; Summary: Greater alignment with the AHEI-P during the first or second trimester of pregnancy was not associated with risk of SGA or LGA.
Rodríguez-Bernal, 2010^39^; PCS, Spain, INMA-Valencia (Infancia y medio Ambiente – Valencia); Analytic N=782; - Age (y): (%): <25: 11; 25-29: 35; 30-34: 38; ≥35: 16; - Race/Ethnicity (%): Country of origin: Spain: 88; Latin American: 8; Other 3; - SEP (%):; - ○ Educational level: Primary school: 33; Secondary school: 43; University degree: 24; - ○ SES: Managerial and senior professionals & intermediate occupations: 16; Skilled, nonmanual workers: 24; Skilled and unskilled manual workers: 61; - ○ Working during pregnancy: 83; - Pre-pregnancy BMI: (%): <18.5: 4; >25: 28; - Smoking (%):; - ○ TM1: 18; - ○ All pregnancy: 24 | AHEI-P (quintiles of alignment); FFQ at: 10-13 GW; DP Description:; - Positive components: vegetables (5 svg/d), fruit (4 svg/d), nuts and soy (1 svg/d), ratio of white meat (fish and poultry) to red meat (≥4:1), cereal fiber (15g/d), ratio of polyunsaturated to saturated fat (≥1), and folate (≥600g/d), calcium (≥1000mg/d), and iron (≥27mg/d) from foods; - Negative components: trans fat; Outcomes:; - SGA - Fetal growth restriction by weight: <80% CI lower limit of prediction intervals. Predicted BW using a customized model, taking into account maternal preconception weight, height, and parity, paternal height, and infant sex and GA. | Fetal Growth Restriction by Weight; Multiple logistic regression; OR (95% CI); Quintile 2 vs Quintile 1 (Ref): 0.55; (0.28, 1.08); Quintile 3 vs Quintile 1 (Ref): 0.35; (0.16, 0.76); Quintile 4 vs Quintile 1 (Ref): 0.51; (0.26, 0.99); Quintile 5 vs Quintile 1 (Ref): 0.24; (0.10, 0.55) | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI; Other covariates: GWG during TM1, folic acid supplement use; Funding: Instituto de Salud Carlos III, FISFEDER, and Conselleria de Sanitat Generalitat Valenciana; Summary: Higher alignment with the AHEI-P was associated with lower risk of fetal growth restriction by weight.
Santos, 2021^40^; PCS, Brazil, Brazilian Unified Health System of Ribeirão Preto; Analytic N=547; - Age (y): 27.2±5.3; - Race/Ethnicity (%): Non-White: 57.4; White: 42.6; - SEP:; - ○ Socioeconomic stratum (Brazil Economic Classification Criterion, %): A+B (Highest): 19.2; D+E (Lowest): 13.2; - ○ Education (y, %): <4: 2.4; ≥9: 67.3; - Pre-pregnancy BMI (%):T1: 26.4±5.2; T2: 25.7±5.0; T3: 24.5±4.2, p=0.001; - Current DM or GDM (%): 0.0; - Smoking (%):; - ○ Never: 79.5; - ○ Ex-smoker: 10.1; - ○ Current: 10.4 | IQDAG (tertiles of alignment); 24 HR at: 24-39 GW (2, 10 d apart); DP Description:; - Positive components: (/1000 kcal): vegetables ≥1.5 svg; legumes ≥0.05 svg; fresh fruits ≥1.5 svg; fibers ≥28.0 g; omega-3 ≥1.4 g; calcium ≥800 mg; folate ≥520 ug; iron ≥22 mg; - Negative components: ultra-processed foods ≥45% of kcal; Outcomes:; - SGA: <10%ile based on INTERGROWTH-21st reference growth curves; - LGA: ≥90%ile; - LBW: <2,500 g; - Macrosomia: ≥4,000 g | SGA; Logistic Regression; OR (95% CI) n=486; T2 vs T1: 1.27 (0.62, 2.62); T3 vs T1: 0.85 (0.39, 1.84); p-trend: 0.67; LGA; Logistic Regression; OR (95% CI), n=491; T2 vs T1: 0.55 (0.28, 1.06); T3 vs T1: 0.44 (0.22, 0.90); p-trend: 0.02; LBW; Logistic Regression; OR (95% CI), n=514; T2 vs T1: 0.75 (0.22, 2.59); T3 vs T1: 0.71 (0.20, 2.49); p-trend: 0.64; Macrosomia; Logistic Regression; OR (95% CI), n=526; T2 vs T1: 0.66 (0.26, 1.70); T3 vs T1: 0.87 (0.33, 2.29); p-trend: 0.76 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: Infant sex, maternal height (meters), physical activity, mean weekly GWG, GW at birth, mode of delivery, TEI, and energy underreporting (yes/no); Funding: São Paulo Research Foundation, National Council for Scientific and Technological Development; Summary: Alignment with the IQDAG was associated with lower risk of LGA, but was not associated with risk of SGA, LBW, or macrosomia.
Sun, 2023^41^; PCS, China, Nanchong Prefecture of Sichuan Province; Analytic N=560; - Age (y): 28.17±4.69; - SEP: SES (%; based on maternal education, annual per capita income of family, and household assets): Low: 32.86; Medium: 32.14; High: 35.00; - Pre-pregnancy BMI (%):; - ○ Underweight: 6.43; - ○ Overweight/obesity: 37.86; - Current HDP (%): GHTN: 5.18 | Dietary diversity score (continuous, per 1 unit increase); MDD (dichotomous, 5 or more vs 4 or less); 24 HR at: ≥14 GW; DP Description:; [underlined: Dietary diversity score and Minimum dietary diversity] [underlined: (MDD)]; - Positive components: starchy staples, beans and peas, nuts and seeds, dairy, flesh foods (meat, fish), eggs, vitamin A-rich dark green vegetables, other vitamin A-rich fruits and vegetables, other vegetables, other fruits; Outcomes:; - SGA: <10%ile, by GA- and sex-specific national growth standards | SGA; Poisson regression; RR (95% CI); Per 1 unit increase: 0.77 (0.61, 0.97), p=0.03; MDD, GWG interaction; Adequate GWG and MDD 5 or higher (Ref); Inadequate GWG and MDD 5 or higher: 2.21 (1.16, 4.19), p<0.001; Adequate GWG and MDD <5: 1.59 (0.45, 5.61); Inadequate GWG and MDD <5: 6.13 (2.89, 12.99), p<0.001; MDD, PPBMI interaction Not underweight and MDD 5 or higher (Ref); Underweight and MDD 5 or higher: 0.85 (0.55, 1.32); Not underweight and MDD <5: 1.78 (0.92, 3.43); Underweight and MDD <5: 9.02 (7.71, 10.55), p<0.001 | Key confounders accounted for: Parity, Age, SEP, Pre-pregnancy BMI, Current HDP; Other covariates: GWG, folic acid supplementation; Funding: Enlight Foundation; Science and Technology Department of Sichuan Province; Summary: Higher alignment with a dietary diversity score was associated with lower risk of SGA. MDD interacted with both GWG and PPBMI, with higher risk of SGA with inadequate MDD and inadequate GWG or underweight PPBMI.
Xu, 2023^43^; PCS, Australia, CHAT (Communicating Healthy Beginnings Advice by Telephone trial); Analytic N=1132; - Age (y): (%): <30: 32, ≥30: 68; - SEP (%):; - ○ Household income: <$80k: 38, ≥$80k: 62; - ○ Employed: 62; - ○ Education: ≥HS to technical and further education/diploma: 34, University/tertiary: 66; - Pre-pregnancy BMI (%):; - ○ Underweight: 4; - ○ Overweight: 21; - ○ Obesity: 14; - Current DM (%): DM (including GDM): 32; - Smoking (%): Yes: 3 | Dietary behaviour score; Junk food score; (continuous, per 1 unit increase) Survey at: 28-34 GW; DP Description:; [underlined: Dietary behaviour score]; - Positive components: fruit, vegetables.; - Negative components: processed meat, fast food, chips, soft drink; [underlined: Junk food score]; - Positive components: processed meat, fast food, chips, soft drink; Outcomes:; - LBW: <2500 g; - Macrosomia: ≥4000 g | LBW; Logistic regression; [underlined: Dietary behaviour score]: 1.02 (0.78, 1.33), p=0.895; [underlined: Junk food score]: 1.00 (0.75, 1.34), p=0.994; Macrosomia; Logistic regression; RR (95% CI); [underlined: Dietary behaviour score]: 0.84 (0.71, 0.99), p=0.047; [underlined: Junk food score]: 1.31 (1.07, 1.60), p=0.009 | Key confounders accounted for: Smoking, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: Language spoken at home, gestational age, infant sex, intervention allocations; Funding: NSW Health Translational Research Grant Scheme; Summary: Higher alignment with the dietary behaviour score was associated with lower risk of macrosomia and was not associated with LBW.; Higher alignment with the junk food score was associated with higher risk of macrosomia and was not associated with LBW.
Yee, 2020^45^; PCS, United States, nuMoM2b (Nulliparous Pregnancy Outcomes Study: Monitoring Mothers-to-Be); Analytic N =8,259; (Q1, Q4); - Age (y): 23.9±5.2; 29.9±4.5, p<0.001; - Race/Ethnicity (%): NHW: 47.8; 74.4; NHB: 24.0; 2.8; Hispanic: 20.3; 11.9; Other: 6.3; 4.0; Asian: 1.5; 6.9, p<0.001; - SEP:; - ○ Public insurance (%): 50.7; 8.4, p<0.001; - ○ Household income <200% FPL (%): 55.7; 12.4, p<0.001; - ○ ≥Some college (%): 82.0; 98.8, p<0.001; - Pre-pregnancy BMI: 27.1±7.3; 24.9±4.9, p<0.001; - Current HDP (%):; - ○ Chronic HTN: 3.3; 1.2, p<0.001; - ○ HDP: 25.9; 20.3, p<0.001; - Current DM (%):; - ○ Pregestational DM: 2.0; 0.8, p=0.018; - ○ GDM: ~4.4; - Smoking (%): Ever used tobacco: 50.7; 36.6, p<0.001 | HEI-2010 (quartiles of alignment); FFQ at: 6-13 GW; DP Description:; - Positive components: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids; - Negative components: Refined Grains; Empty Calories (i.e., energy from solid fats, alcohol, and added sugars); Sodium; Outcomes:; - SGA <10%ile, by Alexander criteria; - LBW <2500g; - Macrosomia >4000g | SGA; Multivariable Poisson Regression; RR (95% CI); Q1 vs. Q4 (Ref): 1.03 (0.83, 1.27), p≥0.05; Q2 vs. Q4 (Ref): 1.01 (0.83, 1.23), p≥0.05; Q3 vs. Q4 (Ref): 0.88 (0.72, 1.07), p≥0.05; LBW; Multivariable Poisson Regression; RR (95% CI); Q1 vs. Q4 (Ref): 1.09 (0.83, 1.44), p≥0.05; Q2 vs. Q4 (Ref): 1.01 (0.78, 1.31), p≥0.05; Q3 vs. Q4 (Ref): 0.86 (0.66, 1.13), p≥0.05; Macrosomia; Multivariable Poisson Regression; RR (95% CI); Q1 vs. Q4 (Ref): 0.63 (0.49, 0.81), p<0.05; Q2 vs. Q4 (Ref): 0.81 (0.65, 0.99), p<0.05; Q3 vs. Q4 (Ref): 0.85 (0.70, 1.04), p≥0.05 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: Chronic HTN, Mental health disorder, Marital status; Funding: NICHD; Clinical and Translational Science Institutes of Indiana University and UC Irvine; Summary: Alignment with the HEI-2010 was not associated with risk of SGA or LBW. Lower alignment (Q1 or Q2) versus Q4 intake was statistically associated with lower risk of macrosomia. Q3 intake was not statistically significantly associated with risk of macrosomia.
Yisahak, 2021^46^; PCS, United States, NICHD Fetal Growth Studies-Singletons; Analytic N=1,948; - Age (y):; - ○ PCA pattern 1: Q1: 29.5±5.4, Q4: 25.4±5.4, p<0.001; - ○ Other DPs: Q1: ~26, Q4: ~30, p<0.001; - Race/Ethnicity (%):; - ○ PCA pattern 1 (%), p<0.001: NHW: Q1: 16, Q4: 13; NHB: Q1: 19, Q4: 50; Hispanic: Q1: 29, Q4: 29; AAPI: Q1: 36, Q4: 8; - ○ Other DPs (%), p<0.001: NHW: Q1: ~15, Q4: ~28; NHB: Q1: ~49, Q4: ~18; Hispanic: Q1: ~26, Q4: ~26; AAPI: Q1: ~10, Q4: ~29; - SEP:; - PCA pattern 1 (%):; - ○ Education <HS: Q1: 13, Q4: 15; HS or equivalent: Q1: 15, Q4: 29; Postgraduate: Q1: 19, Q4: 9, p<0.001; - ○ Income ($) <30k: Q1: 28, Q4: 50; ≥100k: Q1: 24, Q4: 14, p<0.001; - ○ Full-time school or work: Q1: 65, Q4: 68; - ○ Insurance (private/managed care): Q1: 66, Q4: 43, p<0.001; - Other DPs (%):; - ○ Education <HS: Q1: ~15, Q4: ~9; HS or equivalent: Q1: ~27, Q4: ~13; Postgraduate: Q1: ~7, Q4: ~28, p<0.001; - ○ Income ($) <30k: Q1: 47, Q4: 23; ≥100k: Q1: 11, Q4: 38, p<0.001; - ○ Full-time school or work: Q1: 67, Q4: 71; - ○ Insurance (private/managed care): Q1: 48, Q4: 72, p<0.001; - Pre-pregnancy BMI: Q1: ~26.1, Q4: 24.2, p<0.001; - Smoking (%): With obesity: n=17, Without obesity: 0.0 | AHEI-2010, aMed, DASH (quartiles of alignment); FFQ at: 8-13 GW; DP Description:; [underlined: AHEI-2010]; - Positive components: vegetables, fruits, whole grains, nuts and legumes, long-chain omega-3 fatty acids (EPA and DHA), PUFAs.; - Negative components: SSB red/processed meats, trans fat, sodium. Modified to eliminate alcohol component.; [underlined: aMed]; - Positive components: vegetables excluding potatoes, legumes, fruit, nuts, whole grains, fish, ratio of MUFA:SFA.; - Negative components: red and processed meats. Modified to eliminate alcohol component.; [underlined: DASH]; - Positive components: vegetables, fruits, whole grains, low-fat dairy, nuts, seeds, legumes.; - Negative components: red and processed meat, SSB, sodium.; Outcomes:; - SGA <10%ile, by sex-specific U.S. reference (Duryea); - LGA ≥90%ile; - LBW <2500g; - Macrosomia ≥4000g | SGA; Logistic regression; OR (95% CI); [underlined: AHEI-2010]; Q2 vs Q1 (Ref): 0.76 (0.47, 1.25); Q3 vs Q1 (Ref): 0.80 (0.48, 1.31); Q4 vs Q1 (Ref): 0.55 (0.30, 1.01); p trend: 0.11; [underlined: aMED]; Q2 vs Q1 (Ref): 1.22 (0.71, 2.11); Q3 vs Q1 (Ref): 0.89 (0.53, 1.51); Q4 vs Q1 (Ref): 0.60 (0.29, 1.22); p trend: 0.12; [underlined: DASH]; Q2 vs Q1 (Ref): 0.85 (0.50, 1.46); Q3 vs Q1 (Ref): 0.86 (0.51, 1.45); Q4 vs Q1 (Ref): 0.78 (0.43, 1.43); p trend: 0.43; LGA; Logistic regression; OR (95% CI); [underlined: AHEI-2010]; Q2 vs Q1 (Ref): 1.73 (1.02, 2.92); Q3 vs Q1 (Ref): 1.18 (0.67, 2.07); Q4 vs Q1 (Ref): 0.91 (0.48, 1.72); p trend: 0.85; [underlined: aMED]; Q2 vs Q1 (Ref): 1.53 (0.84, 1.51); Q3 vs Q1 (Ref): 1.81 (1.03, 3.19); Q4 vs Q1 (Ref): 1.66 (0.85, 3.25); p trend: 0.14; [underlined: DASH]; Q2 vs Q1 (Ref): 1.29 (0.68, 2.46); Q3 vs Q1 (Ref): 1.75 (0.95, 3.23); Q4 vs Q1 (Ref): 1.73 (0.88, 3.40); p trend: 0.094; LBW; Logistic regression; OR (95% CI); [underlined: AHEI-2010]; Q2 vs Q1 (Ref): 0.73 (0.39, 1.38); Q3 vs Q1 (Ref): 0.64 (0.33, 1.22); Q4 vs Q1 (Ref): 0.48 (0.22, 1.06); p trend: 0.065; [underlined: aMED]; Q2 vs Q1 (Ref): 0.89 (0.47, 1.69); Q3 vs Q1 (Ref): 0.49 (0.25, 0.95); Q4 vs Q1 (Ref): 0.42 (0.18, 1.00); p trend: 0.024; [underlined: DASH]; Q2 vs Q1 (Ref): 1.15 (0.63, 2.12); Q3 vs Q1 (Ref): 0.73 (0.38, 1.40); Q4 vs Q1 (Ref): 0.76 (0.34, 1.69); p trend: 0.33; Macrosomia; Logistic regression; OR (95% CI); [underlined: AHEI-2010]; Q2 vs Q1 (Ref): 1.31 (0.75, 2.27); Q3 vs Q1 (Ref): 1.03 (0.57, 1.85); Q4 vs Q1 (Ref): 0.95 (0.50, 1.81); p trend: 0.87; [underlined: aMED]; Q2 vs Q1 (Ref): 1.61 (0.83, 3.14); Q3 vs Q1 (Ref): 1.89 (1.02, 3.48); Q4 vs Q1 (Ref): 1.94 (0.96, 3.94); p trend: 0.063; [underlined: DASH]; Q2 vs Q1 (Ref): 1.25 (0.63, 2.48); Q3 vs Q1 (Ref): 1.88 (0.98, 3.58); Q4 vs Q1 (Ref): 1.77 (0.88, 3.58); p trend: 0.075 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, income, current job/student status, insurance coverage, Pre-pregnancy BMI; Other covariates: height, marital status, study site, infant sex, total weekly physical activity, total daily energy intake; Funding: NICHD; American Recovery and Reinvestment Act; Summary: Greater alignment with the aMED was associated with lower risk of LBW, but not macrosomia, LGA, or SGA. Alignment with AHEI-2010 and DASH were not associated with risk of LBW, macrosomia, LGA, or SGA.
Zhu, 2019^48^; PCS, United States, PETALS (Pregnancy Environment and Lifestyle Study); Analytic N=2,269; (HEI-2010 Q1, Q4); - Age (y, %): p<0.001; 18-24: 24.3, 9.0; 25-29: 28.9, 26.1; 30-34: 28.9, 38.3; ≥35: 17.8, 26.6; - Race/Ethnicity (%): p<0.001; Hispanic: 43.2, 38.8; Asian/Pacific Islander: 21.9, 24.3; NHW: 17.3, 28.4; African American: 13.6, 4.9; Other: 4.1, 3.5; - SEP: p<0.001; - ○ Education (%): ≤HS: 21.2, 8.5; Some college: 43.0, 30.2; ≥College graduate: 35.8, 61.4; - ○ Household income (%): <$50k: 42.5, 24.7; ≥$150k: 10.6, 22.4; - Pre-pregnancy BMI: p=0.003; <18.5: 3.9, 2.8; 25.0-29.9: 30.2, 27.5; ≥30.0: 30.9, 23.6; - Current HDP (%): HDP: 10.4, 8.5; - Current DM (%): GDM: 10.2, 11.6; - Smoking (%): In pregnancy: 1.2, 0.0, p=0.008 | HEI-2010 (by quartiles of alignment; ≤80 vs >80); FFQ at: 10-13 GW; DP Description:; - Positive components: total fruit, whole fruit, total vegetables, greens and beans, whole grains, dairy, total protein foods, seafood and plant proteins, fatty acids.; - Negative components: refined grains, sodium, empty calories from solid fats and added sugars.; - Alcohol component excluded from empty calories; Outcomes:; - SGA: <10%ile, by sex-, gestational age- and racial/ethnic-specific distribution of BW in the underlying population; - LGA: >90%ile | SGA; Poisson regression; RR (95% CI); Q1 vs Q4 (Ref): 0.92 (0.61, 1.38); Q2 vs Q4 (Ref): 0.83 (0.55, 1.25); Q3 vs Q4 (Ref): 1.09 (0.75, 1.60); p trend: 0.454; ≤80 vs >80 (Ref): 0.96 (0.69, 1.36; LGA; Poisson regression; RR (95% CI); [underlined: All]; Q1 vs Q4 (Ref): 1.76 (1.08, 2.87); Q2 vs Q4 (Ref): 1.71 (1.06, 2.75); Q3 vs Q4 (Ref): 1.67 (1.03, 2.69); p trend: 0.037; ≤80 vs >80 (Ref): 1.81 (1.15, 2.84); [underlined: Non-GDM (n=1,849)]; Q1 vs Q4 (Ref): 1.99 (95% CI >1.00); Q2 vs Q4 (Ref): 1.90 (95% CI >1.00); Q3 vs Q4 (Ref): 1.85 (95% CI >1.00); [underlined: GDM (n=226)]; Q1 vs Q4 (Ref): 0.98 (95% CI includes 1.00); Q2 vs Q4 (Ref): 0.94 (95% CI includes 1.00); Q3 vs Q4 (Ref): 1.04 (95% CI includes 1.00); HEI-2010 by GDM interaction: p<0.001; [underlined: Term births (n=1,977)]; Q1 vs Q4 (Ref): 1.67 (1.01, 2.75); Q2 vs Q4 (Ref): 1.59 (0.98, 2.57); Q3 vs Q4 (Ref): 1.52 (0.93, 2.47); [underlined: Without HDP (n=1,948)]; Q1 vs Q4 (Ref): 1.78 (1.09, 2.92); Q2 vs Q4 (Ref): 1.72 (1.03, 2.88); Q3 vs Q4 (Ref): 1.63 (0.99, 2.68) | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy Other covariates: pre-existing HTN, total daily energy intake during pregnancy, PA during pregnancy, prenatal supplement use, GA at delivery; Funding: NIEHS; NIH Building Interdisciplinary Research Careers in Women’s Health Program; HRSA; NIH ECHO Program; Summary: Alignment with the HEI-2010 was associated with lower risk of LGA. Alignment with the HEI-2010 was not associated with risk of SGA.
Factor/Cluster Analysis
Ancira-Moreno, 2020^50^; PCS, Mexico, PRINCESA (Pregnancy Research on Inflammation, Nutrition & City Environment: Systematic Analyses); Analytic N=660; - Age (y): 25.08±5.8; - SEP (%): Education ≤9 y: 56.0; - Pre-pregnancy BMI:; - ○ 25.72±5.2; - ○ (%): BMI ≥25 to <30: 32.5; ≥30 to <35: 12.4; ≥35: 5.0 | Healthier DP & Mixed DP (Continuous alignment; Tertiles of alignment); 24HR at: TM2 and TM3; DP Description:; [underlined: Healthier DP]; Higher intakes of white meat and eggs, low fat dairy products, cereals and tubers, fruits and vegetables; Lower intakes of high saturated fat and/or added sugar foods, SSB, legumes.; [underlined: Mixed DP]; Higher intakes of SSBs, red and processed meat, cereals and tubers, supplements; Lower intakes of oils and fats, high saturated fat and/or added sugar foods, white meat and eggs, low fat dairy products.; Outcomes:; - LBW: <2,500 g | LBW; Logistic regression; OR (95% CI); [underlined: Healthier dietary pattern]; Continuous: 0.85 (0.59, 1.23), p=0.41; T2 vs T1 (ref): 0.66 (0.2, 1.5), p=0.33; T3 vs T1 (ref): 0.65 (0.2, 1.5), p=0.33; [underlined: Mixed dietary pattern]; Continuous: 1.11 (0.76, 1.56), p=0.65; T2 vs T1 (ref): 0.98 (0.4, 2.2), p=0.94; T3 vs T1 (ref): 1.12 (0.4, 2.5), p=0.78 | Key confounders accounted for:; Parity, Age, SEP, Pre-pregnancy BMI Other covariates: Energy intake, GWG, maternal height, marital status, term of gestation, baby’s sex; Funding: NIEHS; Summary: Alignment with a "healthier dietary pattern" and "mixed dietary pattern" was not associated with risk of LBW.
Barchitta, 2023^2^; PCS, Italy, MAMI-MED; Exposure N=Cluster 2: 509, Comparator N=Cluster 1: 158; - Age (y): Median (IQR): 31 (7); - SEP:; - ○ High education level: 24.9%; - ○ Employed: 50.7%; - Pre-pregnancy BMI: Median (IQR): 23.2 (5.8); - Smoking (%): No smoking during pregnancy: 91 | Cluster 2 vs Cluster 1; FFQ at: TM1; DP Description:; [underlined: Cluster 1]; Higher intake of potatoes, cooked and raw vegetables, legumes, fruits, nuts, yogurt, rice, wholemeal bread, white meat, offal, fish, eggs, butter and margarine, coffee, tea, soup.; [underlined: Cluster 2]; Higher intake of milk, pasta, white bread, shellfish, vegetable and olive oils, sweets, fruit juices, dipping sauces, salty snacks, fries; Outcomes:; - SGA: NR; - LGA: NR | SGA; Logistic regression; OR (95% CI); Cluster 2 vs Cluster 1 (Ref): 0.537; (0.262, 1.104), p=0.091; LGA; Logistic regression; OR (95% CI); Cluster 2 vs Cluster 1 (Ref): 2.213; (1.047, 4.679), p=0.038 | Key confounders accounted for: Parity, Smoking, Age, SEP, Pre-pregnancy BMI; Other covariates: GWG, TEI; Funding: University of Catania, Italy; Summary: Alignment with Cluster 2, compared to Cluster 1, was associated with greater risk of LGA. Alignment with Cluster 2, compared to Cluster 1, was not associated with SGA.
Berube, 2023^3^; PCS, United States, StEP Trial (Starting Early Program Trial); Analytic N=498; - Age (y): 28±6; - Race/Ethnicity (%): Hispanic/Latina: 100; - SEP (%):; - ○ ≥HS education: 66.4; - ○ Employed: 24.8; - Pre-pregnancy BMI: 27.5±5.5 | Western DP, Fruits and vegetables DP (tertiles of alignment); FFQ at: 28-32 GW; DP Description:; [underlined: Western DP]; Higher intake of cakes, pies, and cookies, processed meats, American dishes, candy, sweetened beverages, salty snacks.; [underlined: Fruits and vegetables DP]; Higher intake of nonstarchy vegetables, starchy vegetables, beans and peas, meat/vegetable soups, whole fresh fruit.; Outcomes:; - SGA: ≤10%ile based on Fenton growth curves; - LGA: ≥90%ile | SGA; Logistic regression; OR (95% CI); [underlined: Western DP]; T2 vs T1 (Ref): 0.7 (0.3, 1.8); T3 vs T1 (Ref): 0.6 (0.1, 2.4); [underlined: Fruits and vegetables DP]; T2 vs T1 (Ref): 0.8 (0.3, 1.8); T3 vs T1 (Ref): 0.4 (0.1, 1.2); LGA; Logistic regression; OR (95% CI); [underlined: Western DP]; T2 vs T1 (Ref): 1.2 (0.5, 3.0); T3 vs T1 (Ref): 0.5 (0.1, 2.1); [underlined: Fruits and vegetables DP]; T2 vs T1 (Ref): 0.6 (0.2, 1.8); T3 vs T1 (Ref): 2.3 (0.9, 6.2) | Key confounders accounted for: Parity, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI; Other covariates: Marital status, physical activity, total energy; Funding: NIFA; NICHD; Summary: Alignment with Western DP, Fruits and vegetables DP, and the HEI-2015 was not associated with risk of SGA or LGA.
Bodnar, 2024^4^; PCS, United States, nuMoM2b (Nulliparous Pregnancy Outcomes Study: Monitoring Mothers-to-Be); Exposure N=FVGP: 1347; SS: 2789; BGM: 1742, Comparator N=2381 For FSS; FVGP; SS; BGM; - Age (y, %): <25: 61, 8, 12, 48; 25 to 34: 35, 74, 75, 45; ≥35: 4, 18, 13, 7; - Race/Ethnicity (%): NHW: 48, 76, 84, 38; NHB: 27, 3, 2, 11; Hispanic: 16, 10, 8, 38; Other: 9, 11, 6, 13; - SEP: (% or median (IQR)); - ○ Married: 33, 89, 85, 56; - ○ Private Insurance: 48, 92, 91, 54; - ○ Currently employed: 68, 91, 93, 71; - ○ Acculturation: US-born (self and parents): 80, 70, 82, 46; USborn/immigrant parent: 14, 12, 11, 19; Born outside US, immigrated at <18 y: 4, 9, 4, 18; Born outside US, immigrated at ≥18 y: 2, 9, 3, 18; - ○ Education: ≤HS: 38, 3, 4, 24; College graduate: 15, 38, 41, 24; Graduate degree: 6, 47, 35, 14; - ○ Area Deprivation Index: 59 (55), 24 (34), 27 (33), 45 (62); - ○ Percent of neighborhood in poverty: 18 (22), 11 (13), 10 (11), 17 (20); - Pre-pregnancy BMI: (%) <18.5: 6, 4, 2, 5; 18.5 to <25: 46, 69, 60, 54; 25 to <30: 23, 18, 22, 23; ≥30: 25, 10, 16, 18; - Current HDP (%): PE: Total 8.6, FSS: 11; FVGP: 6.4; SS: 7.8; BGM: 8.3; - Current DM (%): GDM: Total: 4.9, FSS: 5.5; FVGP: 4.1; SS: 4.7; BGM: 5.2; - Smoking (%): Preconception smoker: 30, 6, 14, 12 | Greater alignment with FVGP; SS; or BGM vs FSS DP; FFQ at: 6-13 GW; DP Description:; [underlined: High fruits, vegetables, whole grains, and plant proteins (FVGP)]; Higher intake of vegetable medley/other vegetables, apples/pears, tomatoes, lettuce, broccoli, bananas, spinach/greens, strawberries/ other berries, avocado, citrus fruits, tofu/meat substitutes, peaches/plums/ apricots/nectarines, yogurt, salad dressing, peas/string beans, nuts/seeds/nut or seed mixed dishes, sweet potatoes, other fruit/fruit salad, melon, coffee; [underlined: Sandwiches and snacks (SS)]; Higher intake of coffee, alcoholic beverages, whole wheat bread, cold cuts, skim milk, diet soda/diet fruit drinks, pretzels/fat-free crackers/rice cakes, nuts/ seeds/nut or seed mixed dishes, condiments, salad dressing, cream, unfried chicken or turkey/mixed dishes, crackers, reduced fat cheese, jam/jelly, white breads, sugars/honey, regular cheese, mayonnaise, nondairy creamer/cream substitutes; [underlined: Beverages, refined grains, and mixed dishes (BGM)] Higher intake of reduced fat milk, 100% juice (not orange or grapefruit), rice/rice mixed dishes, 100% orange or grapefruit juice, Mexican mixed dishes, dried beans, soup, liver/other organ meats, whole milk, cold cereals, hot cereal, oils, vegetable juice, other white potatoes, vegetable mixed dishes, other meat/other meat mixed dishes, syrups/toppings, eggs/egg mixed dishes, pancakes/waffles/French toast/Pop Tarts, coleslaw; [underlined: High fat, sugar, and sodium (FSS)]; Higher intake of regular soda, fried chicken or fried turkey, fried white potatoes, burgers, sausage/ franks/bacon/ribs, fruit drinks, chips/popcorn/other salty snacks, candy, pizza, grain desserts, other meat/other meat mixed dishes, white yeast breads, pancakes/waffles/French toast/Pop Tarts, dairy desserts, margarine, quick breads, beef/beef mixed dishes, crackers, other white potatoes, mayonnaise HEI-2015 score and nearly all components of Healthy US-Style Eating Pattern were highest in the FVGP DP and lowest in the FSS DP. There were no meaningful differences in dairy, total protein foods, meats, poultry, and eggs, or seafood intake by DP.; Outcomes:; - SGA: <10%ile based on NICHD ultrasound-based intrauterine fetal weight standards | SGA; Targeted minimum loss-based estimation; Adjusted number of excess cases per 100 pregnancies (95% CI); [underlined: FVGP]: −0.35 (−2.7, 2.0); [underlined: SS]: −2.0 (−3.8, −0.14); [underlined: BGM]: −1.1 (−3.3, 1.00); [underlined: FSS]: 0 (Ref) | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy Other covariates: Other sociodemographic factors (marital status, whether the pregnancy was planned), other medical factors (gravidity, nausea and vomiting, season of conception and assisted reproductive technologies), other behaviors (binge drinking, prenatal vitamin use, PA), psychosocial factors (depressive symptoms, anxiety, perceived stress, resilience, health literacy, and sleep satisfaction).; Funding: NICHD; Indiana Univ; Univ of California Irvine; Summary: High alignment with the SS DP versus high alignment with the FSS DP was associated with reduced risk of SGA. High alignment with the FVGP and BGM DP versus high alignment with the FSS DP was not associated with risk of SGA.
Chia, 2016^7^; PCS, Singapore, GUSTO (Growing Up in Singapore Towards healthy Outcomes); Analytic N=923; By VFR score (Quintile 1; 3; 5); - Age (y): 28.2±5.1; 29.8±5.0; 32.4±4.8; - Race/Ethnicity (%): Chinese: 35; 50; 76; Malayan: 56; 33; 5; Indian: 9; 17; 20; - SEP: Education: None, primary, or secondary: 41; 33; 21; Postsecondary: 40; 38; 31; University: 19; 28; 48; - Pre-pregnancy BMI: 22.5±4.7; 22.7±4.7; 22.1±3.6; - Current HDP (%): 6.0; 4.3; 3.3; - Current DM (%):; - ○ No serious health conditions such as T1 DM; - ○ GDM: 12; 12; 26; - Smoking (%): Current Smoker: 7.1; 2.1; 0.5 | VFR, SfN, and PCP DP (higher vs lower alignment) 24 HR, 3-d food diary at: 26-28 GW; DP Description:; [underlined: Vegetable, fruit, and white rice (VFR) DP]; - Higher intakes of vegetables, fruits, plain white rice, whole-grain bread, fish, and nuts and seeds.; - Lower intakes of fried potatoes, burgers, carbonated and sweetened drinks, and flavored rice; [underlined: Seafood and noodle (SfN) DP]; - Higher intakes of soup, seafood, fish and seafood products, noodles (flavored and in soup), and low-fat red meat; - Lower intakes of legumes, ethnic bread, white rice, and curry-based gravies; [underlined: Pasta, cheese, and processed meat (PCP) DP]; - Higher intake of pasta-, tomato-, and cream-based gravies, cheese, and processed meat; Outcomes:; - SGA: <10%ile based on a global BW reference; - LGA: >90%ile | SGA vs AGA; Multinomial Logistic Regression, Higher vs lower adherence (Ref); OR (95% CI); [underlined: VFR]: 1.03 (0.82, 1.30); [underlined: SfN]: 1.17 (0.92, 1.48); [underlined: PCP]: 1.09 (0.89, 1.33); LGA vs AGA; Multinomial Logistic Regression, Higher vs lower adherence (Ref); OR (95% CI); [underlined: VFR]: 1.31 (1.06, 1.62); [underlined: SfN]: 1.17 (0.92, 1.47); [underlined: PCP]: 1.18 (0.99, 1.39); Subgroup analysis with DP from 3d food records (n=212) showed no statistically significant association between VFR or SfN and SGA or LGA. | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: Infant sex, and maternal TEI, weight gain until 26–28 wk of gestation, height, alcohol use, and other dietary patterns; Funding: Singapore National Research Foundation; Agency for Science, Technology, and Research; Nestec; Summary: Greater alignment with the vegetable, fruit, and white rice DP was associated with a higher risk of LGA. There was no association between the seafood and noodle DP or the pasta, cheese, and processed meat DP and SGA or LGA.
de Seymour, 2022^8^; PCS, China, CLIMB (Complex Lipids in Mothers and Babies); Analytic N =962; - Age (y): Median (IQR): 28 (26, 31); - Race/Ethnicity (%): Han ethnicity: 97.9; - SEP:; - ○ Tertiary level education (%): 63.1; - ○ Household income (%): <7k yuan/mo: 19.5; >10k yuan/mo: 44.5; - Baseline BMI: Median (IQR): 21.0 (19.4, 22.9); - Current HDP (%): PE: 1.7; - Current DM (%): GDM: 27.7 | FPV DP & PSO DP (continuous alignment); FFQ at: 11-14 GW; DP Description:; [underlined: Fish, poultry and vegetables (FPV) DP]:; Higher in fish; poultry; legumes and bean products; green leafy vegetables; root vegetables; other vegetables; seafood; fruits; eggs; organ meats; beverages; bread; dairy; soup; nuts; [underlined: Pasta, sweetened beverages, oils and condiments] [underlined: (PSO) DP]:; Higher in pasta; sweetened beverages; oils and condiments; fast food; Outcomes:; - SGA: <10%ile based on references specific to Chongqing; - LGA: >90%ile; - Macrosomia: >4000 g | SGA; Binomial logistic regression; OR (95% CI); [underlined: FPV DP]: 1.119 (0.775, 1.614), p=0.549; [underlined: PSO DP]: 0.937 (0.607, 1.445), p=0.767; LGA; Binomial logistic regression; OR (95% CI); All participants; [underlined: FPV DP]: 1.222 (0.963, 1.552), p=0.100; [underlined: PSO DP]: 0.860 (0.631, 1.172), p=0.340; Sensitivity analysis excluding participants w/ highest and lowest 0.5% of DP scores (N=1207) [underlined: FPV DP]: 1.318 (1.058, 1.641), p=0.014; [underlined: PSO DP]: 0.814 (0.584, 1.135), p=0.225; Macrosomia; Binomial logistic regression; OR (95% CI); All participants; [underlined: FPV DP]: 1.265 (0.913, 1.753), p=0.158; [underlined: PSO DP]: 0.955 (0.653, 1.394), p=0.807; Sensitivity analysis excluding participants w/ highest and lowest 0.5% of DP scores (N=1207); [underlined: FPV DP]: p=0.045 | Key confounders accounted for: Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: CLIMB treatment group; Offspring sex; TEI; Other DP; Funding: Joint Health Research Council New Zealand–National Science Foundation of China; Lottery Health New Zealand; Fonterra Co-operative Group Ltd., New Zealand; New Zealand Ministry for Primary Industries; Summary: When participants with the highest and lowest 0.5% of DP scores were removed from the analysis, alignment with the FPV DP was associated with higher risk of LGA and macrosomia, but results were not significant when including all participants. Alignment with the PSO DP was not associated with LGA or macrosomia and neither DP was associated with risk of SGA.
Englund-Ogge, 2019^11^; PCS, Norway, MoBa (Norwegian Mother and Child Cohort Study); Exposure N=HP: 10,150; HT: 9,754; Comparator N=HW: 9,562 (HW, HP, HT); - Age (y): 28.7±4.5, 31.3±4.1, 30.3±4.8, p<0.001; - SEP:; - ○ Education (%), p<0.001; ≤12 y: 42.6, 14.7, 36.4; ≥17 y: 14.5, 44.9, 18.8; - ○ Household income (%), p<0.001; Both <300k NOK: 33.5, 17.3, 33.1; Both ≥300k NOK: 20.6, 44.5, 19.9; - Pre-pregnancy BMI: 24.6±4.6, 23.1±3.6, 24.1±4.2, p<0.001; - Current DM (%): DM: 0.0; - Smoking (%): p<0.001; - ○ Not during pregnancy: 86.7, 96.5, 90.4; - ○ Daily during pregnancy: 9.0, 1.4, 6.4 | HW DP, HP DP vs HW DP FFQ at: 22 GW; DP Description:; [underlined: High prudent (HP)]; Higher intake of raw and cooked vegetables, salad, onion/leek/garlic, fruit and berries, nuts, vegetable oils, water as beverage, whole grain cereals, poultry, and fibre rich bread.; Lower intake of processed meat products, white bread, pizza/tacos.; [underlined: High western (HW)]; Higher intake of salty snacks, chocolate and sweets, cakes, French fries, white bread, ketchup, sugar sweetened drinks, processed meat products, pasta.; Lower intake of lean fish, fibre rich bread.; [underlined: High traditional (HT)]; Higher intake of boiled potatoes, fish products, gravy, lean fish, margarine, rice pudding, low fat milk, cooked vegetables.; Lower intake of poultry, pizza/tacos.; Individuals in HP were in highest tertile of HP and in lowest or middle tertile of HW and HT.; Individuals in HW were in highest tertile of HW and in lowest or middle tertile of HP and HT.; Individuals in HT were in highest tertile of HT and in lowest or middle tertile of HP and HW.; Outcomes:; - SGA:; - ○ Ultrasound-based: <2SD ultrasound-derived growth curves; - ○ Population-based: <10%ile; - ○ Customized <10%ile ultrasound-derived growth curves accounting for characteristics such as infant sex, maternal weight, height, parity; - LGA:; - ○ Ultrasound-based: >2SD ultrasound-derived growth curves; - ○ Population-based: >90%ile; - ○ Customized: >90%ile ultrasound-derived growth curves accounting for characteristics such as infant sex, maternal weight, height, parity | SGA - ultrasound-based; Logistic regression; OR (95% CI); [underlined: All]; HP vs HW (Ref): 1.25 (1.02, 1.54); HT vs HW (Ref): 1.16 (0.94, 1.43); [underlined: BMI <25]; HP vs HW (Ref): 1.28 (1.00, 1.64); HT vs HW (Ref): 1.29 (1.00, 1.67); [underlined: BMI ɥ25]; HP vs HW (Ref): 1.34 (0.87, 2.30); HT vs HW (Ref): 0.88 (0.52, 1.50); SGA - population-based; Logistic regression; OR (95% CI); [underlined: All]; HP vs HW (Ref): 1.04 (0.94, 1.15); HT vs HW (Ref): 0.91 (0.82, 1.01); [underlined: BMI <25]; HP vs HW (Ref): 1.06 (0.94, 1.19); HT vs HW (Ref): 0.90 (0.80, 1.02); [underlined: BMI ≥25]; HP vs HW (Ref): 1.13 (0.83, 1.52); HT vs HW (Ref): 0.88 (0.66, 1.17); SGA - customized Logistic regression; OR (95% CI); [underlined: All]; HP vs HW (Ref): 1.06 (0.98, 1.15); HP vs HW (Ref): 0.92 (0.84, 0.99); [underlined: BMI <25]; HP vs HW (Ref): 1.05 (0.95, 1.16); HT vs HW (Ref): 0.95 (0.86, 1.05); [underlined: BMI ≥25]; HP vs HW (Ref): 1.10 (0.95, 1.27); HT vs HW (Ref): 0.85 (0.74, 0.97); LGA - ultrasound-based; Logistic regression; OR (95% CI); [underlined: All]; HP vs HW (Ref): 0.87 (0.73, 1.02); HT vs HW (Ref): 1.09 (0.94, 1.26); [underlined: BMI <25]; HP vs HW (Ref): 0.80 (0.63, 1.01); HT vs HW (Ref): 1.14 (0.92, 1.41); [underlined: BMI ≥25]; HP vs HW (Ref): 1.09 (0.79, 1.49); HT vs HW (Ref): 1.05 (0.80, 1.37); LGA - population-based; Logistic regression; OR (95% CI); [underlined: All]; HP vs HW (Ref): 0.84 (0.75, 0.94); HT vs HW (Ref): 1.12 (1.02, 1.24); [underlined: BMI <25]; HP vs HW (Ref): 0.73 (0.63, 0.85); HT vs HW (Ref): 1.12 (0.98, 1.28); [underlined: BMI ≥25]; HP vs HW (Ref): 1.03 (0.87, 1.22); HT vs HW (Ref): 1.13 (0.98, 1.31); LGA - customized; Logistic regression; OR (95% CI); [underlined: All]; HP vs HW (Ref): 0.88 (0.78, 0.99); HP vs HW (Ref): 1.14 (1.03, 1.27); [underlined: BMI <25]; HP vs HW (Ref): 0.89 (0.77, 1.03); HT vs HW (Ref): 1.21 (1.06, 1.39); [underlined: BMI ≥25]; HP vs HW (Ref): 0.90 (0.73, 1.12); HT vs HW (Ref): 1.06 (0.88, 1.27) | Key confounders accounted for: Parity, Smoking, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: TEI, height, alcohol intake; Funding: Norwegian Research Council; Jane and Dan Olsson Foundation; Swedish Medical Society; Swedish government grants; Norwegian Ministry of Health and Care Services and the Ministry of Education and Research; Summary: Alignment with a HT DP compared to alignment with a HW DP was associated with lower risk of SGA (customized definition) among all participants and participants with BMI ≥25 and higher risk of LGA (population-based and customized definition) among all participants.; Alignment with a HP DP compared to alignment with a HW DP was associated with higher risk of SGA (ultrasound-based definition) among all participants and participants with BMI <25 and a lower risk of LGA (population-based and customized definition) among all participants and participants with BMI <25.
Flynn, 2016^12^; PCS, United Kingdom, UPBEAT (U.K. Pregnancies Better Eating and Activity Trial); Analytic N=995 (LGA, SGA), 997; (Macrosomia); - Age (y): 30.5±5.5; - Race/Ethnicity (%): White: 64; Black: 23; Asian: 8; Other: 5; - SEP:; - ○ Education (%): None/GCSE: 20, A level: 16, Degree/higher degree: 40, Vocational qualification: 24; - ○ Index of multiple deprivation (%): 1 (least deprived): 4, 2: 7, 3: 12, 4: 34, 5 (most deprived): 43; - Pre-pregnancy BMI: 36.2±4.7; ≥30: 100%; - Current HDP (%): PE: 4; - Current DM (%):; - ○ GDM: 23; - ○ Pre-pregnancy DM: 0 | Fruit and veg DP, African/Caribbean DP, Processed DP, Snacks DP (quartiles of alignment); FFQ at: 15-18 GW; DP Description:; [underlined: Fruit and veg DP]; Higher intake of bananas, citrus fruit, dried fruit, fresh fruit, green vegetables, pulses, root vegetables, salad vegetables, tropical fruit, yoghurt; [underlined: African/Caribbean DP]; Higher intake of red meat, cassava, white meat, pilau/fried/jollof rice, plantain, white/brown/basmati rice, fish; [underlined: Processed DP]; Higher intake of chocolate, crisps, green vegetables, potatoes, processed/meat products, root vegetables, squash/fizzy drinks, sugar free drinks, takeaway/oven chips; [underlined: Snacks DP]; Higher intake of biscuits/cookies, cakes/pastries, chocolate, full fat cheese, sweets; Outcomes:; - SGA: <10%ile based on WHO growth curves; - LGA: >90%ile; - Macrosomia: >4kg | SGA; Logistic regression; OR (95% CI); [underlined: Fruit and veg DP]; Q2 vs Q1 (Ref): 0.38 (0.17, 0.83); Q3 vs Q1 (Ref): 0.66 (0.33, 1.32); Q4 vs Q1 (Ref): 0.48 (0.23, 1.03); p = 0.073; [underlined: African/Caribbean DP]; Q2 vs Q1 (Ref): 1.30 (0.62, 2.72); Q3 vs Q1 (Ref): 0.46 (0.19, 1.16); Q4 vs Q1 (Ref): 1.10 (0.46, 2.65); p = 0.128; [underlined: Processed DP]; Q2 vs Q1 (Ref): 1.82 (0.86, 3.86); Q3 vs Q1 (Ref): 1.49 (0.66, 3.38); Q4 vs Q1 (Ref): 1.48 (0.65, 3.40); p = 0.479; [underlined: Snacks DP]; Q2 vs Q1 (Ref): 0.93 (0.45, 1.90); Q3 vs Q1 (Ref): 0.68 (0.30, 1.53); Q4 vs Q1 (Ref): 0.76 (0.36, 1.63); p = 0.773; LGA; Logistic regression; OR (95% CI); [underlined: Fruit and veg DP]; Q2 vs Q1 (Ref): 1.39 (0.76, 2.53); Q3 vs Q1 (Ref): 1.41 (0.77, 2.59); Q4 vs Q1 (Ref): 1.70 (0.94, 3.06); p = 0.377; [underlined: African/Caribbean DP]; Q2 vs Q1 (Ref): 1.41 (0.79, 2.50); Q3 vs Q1 (Ref): 1.52 (0.85, 2.71); Q4 vs Q1 (Ref): 1.47 (0.73, 2.97); p = 0.512; [underlined: Processed DP]; Q2 vs Q1 (Ref): 0.93 (0.52, 1.67); Q3 vs Q1 (Ref): 0.77 (0.42, 1.41); Q4 vs Q1 (Ref): 0.85 (0.46, 1.55); p = 0.844; [underlined: Snacks DP]; Q2 vs Q1 (Ref): 1.10 (0.59, 2.07); Q3 vs Q1 (Ref): 1.38 (0.74, 2.57); Q4 vs Q1 (Ref): 1.14 (0.60, 2.15); p = 0.749; Macrosomia; Logistic regression; OR (95% CI); [underlined: Fruit and veg DP]; Q2 vs Q1 (Ref): 0.86 (0.49, 1.51); Q3 vs Q1 (Ref): 1.33 (0.79, 2.27); Q4 vs Q1 (Ref): 1.40 (0.83, 2.36); p = 0.236; [underlined: African/Caribbean DP]; Q2 vs Q1 (Ref): 1.45 (0.86, 2.45); Q3 vs Q1 (Ref): 1.71 (1.01, 2.88); Q4 vs Q1 (Ref): 0.98 (0.50, 1.94); p = 0.114; [underlined: Processed DP]; Q2 vs Q1 (Ref): 0.78 (0.45, 1.33); Q3 vs Q1 (Ref): 0.70 (0.40, 1.21); Q4 vs Q1 (Ref): 0.95 (0.55, 1.61); p = 0.520; [underlined: Snacks DP]; Q2 vs Q1 (Ref): 1.67 (0.92, 3.02); Q3 vs Q1 (Ref): 1.69 (0.93, 3.09); Q4 vs Q1 (Ref): 1.69 (0.93, 3.08) p = 0.286 | Key confounders accounted for: Parity, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, Current HDP; Other covariates: treatment allocation; Funding: NIHR (UK); Scottish Government Health Directorates; Guys and St. Thomas’ Charity; Tommy’s Charity; NHS Foundation Trust; King’s College London; EU Seventh Framework Programme; Summary: Alignment with a fruit and veg DP, an African/Caribbean DP, a Processed DP, and a Snacks DP were not associated with risk of LGA, SGA, or macrosomia except for isolated associations between fruit and veg DP (Q2 vs Q1) and lower risk of SGA, and African/Caribbean DP (Q3 vs Q1) and higher risk of macrosomia.
Grieger, 2014^15^; PCS, Australia, Lyell McEwin; Hospital; Analytic N=309; - Age (y): 26.6±5.4; - Race/Ethnicity (%): Caucasian: 89; Non-Caucasian: 11; - SEP: SES (%): 5 (highest): 5; 4: 5; 3: 3; 2: 30; 1 (lowest): 52; - Pre-pregnancy BMI: 27.6±6.6; - Smoking (n, %): Never/former 211 (68); Quit in pregnancy/current 98 (32) | High-protein/fruit; High-fat/sugar/takeaway; Vegetarian-type DP (continuous, per SD of alignment) FFQ at: 13 GW; DP Description:; [underlined: High-protein/fruit]; Higher intake of fish, meat, chicken, fruit, whole grains; [underlined: High-fat/sugar/takeaway]; Higher intake of takeaway foods, potato chips, refined grains, added sugar; [underlined: Vegetarian-type]; Higher intake of vegetables, whole grains, legumes; Outcomes:; - SGA: <10%ile; - LBW: <2500 g | SGA; [underlined: High protein/fruit]: 0.84 (0.55, 1.28), p=0.41; [underlined: High fat/sugar/take-away]: 1.02 (0.72, 1.46), p=0.90; [underlined: Vegetarian type]: 1.16 (0.82, 1.64), p=0.39; LBW; [underlined: High protein/fruit]: 0.41 (0.13, 1.33), p=0.14; [underlined: High fat/sugar/take-away]: 1.39 (0.87, 2.22), p=0.17; [underlined: Vegetarian type]: 0.93 (0.54, 1.62), p=0.80 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI; Other covariates: Asthma status; Funding: National Health and Medical Research Council Senior Research Fellowship; Summary: No DP were associated with risk of SGA or LBW.
Hajianfar, 2018^16^; PCS, Iran (Islamic Rep. of), Isfahan University of Medical Sciences; Analytic N=812; - Age (y): 29.4±4.85; - Current HDP (%): Excluded participants with "medical conditions"; - Current DM (%): Excluded participants with "medical condition"; - Smoking (%): Current: 0.0 | Healthy DP, Western DP, Traditional DP (Q2, Q3, Q4 vs Q1); FFQ at: 8-16 GW; DP Description:; [underlined: Healthy]; Higher intake of green vegetables, leafy vegetables, colored vegetables, fruit, dairy low fat, poultry, bulky vegetables, red meat, citrus, nuts, fish, olive, marinades, sweat fruit, egg, unsaturated fat.; [underlined: Western]; Higher intake of fruit, citrus, nuts, fish, fruit juice, sweets and dessert, sugar, saturated fat, sweet fruit, potato, legumes, coffee, egg, pizza, high fat dairy, soft drink, whole grain, processed meat. Lower intake of refined grain.; [underlined: Traditional]; Higher intake of colored vegetables, olive, sugar, salt, spices, unsaturated fat, garlic onion, tea, refined grain.; Outcomes:; - LBW: <2500g | LBW; Logistic regression; OR (95% CI); [underlined: Western DP]; Q2 vs Q1 (Ref): 0.84 (0.29, 2.40); Q3 vs Q1 (Ref): 1.89 (0.65, 5.52); Q4 vs Q1 (Ref): 5.51 (1.82, 16.66); p=0.001; [underlined: Traditional DP]; Q2 vs Q1 (Ref): 1.14 (0.49, 2.67); Q3 vs Q1 (Ref): 1.36 (0.58, 3.19); Q4 vs Q1 (Ref): 0.60 (0.32, 1.63) p=0.35; [underlined: Healthy DP]; Q2 vs Q1 (Ref): 1.05 (0.45, 2.43); Q3 vs Q1 (Ref): 1.25 (0.53, 2.91); Q4 vs Q1 (Ref): 0.59 (0.19, 1.79) p=0.48 | Key confounders accounted for: Smoking, Age, SEP, Pre-pregnancy BMI Other covariates: energy intake, PA, delivery status, preterm delivery, intrauterine growth restriction, history of abortion, stillbirth; Funding: Isfahan University of Medical Sciences; Summary: Alignment with a Western DP was associated with higher risk of LBW. Alignment with a Traditional DP or a Healthy DP was not associated with risk of LBW.
Knudsen, 2008^21^; PCS, Denmark, DNBC (Danish National Birth Cohort); Exposure N=Health conscious: 7,479; Intermediate: 29,514, Comparator N=7,619; - Age (y): 29y; (%): <20: 0.8; 20-29: 54.3; 30-39: 44.1; >40: 0.9; - Smoking (%): Ever: 23.4 | Health conscious DP; Intermediate DP vs Western DP; FFQ at: 25 GW; DP Description:; [underlined: Western DP]; - Highest intake of high-fat dairy, refined grains, processed and red meat, animal fat (butter and lard), potatoes, sweets, beer, coffee, and high-energy drinks; - Lowest intake of fruits and vegetables (35% of energy intake from fat); [underlined: Health conscious DP]; - Higher intakes of fruits, vegetables, fish, poultry, breakfast cereals, vegetable juice, and water;; - Lowest intakes of meat and fat of animal origin (25% of energy intake from fat); [underlined: Intermediate DP]; - Higher intakes of low-fat dairy and fruit juice; consumption of the remaining food groups in between Western and Health conscious DPs (30% of energy intake from fat); Outcomes:; - SGA: <2.5%ile based on sex-specific Scandanavian intrauterine growth curves | SGA; Logistic regression; OR (95% CI); [underlined: Health conscious DP] vs. Western; DP (Ref): 0.74 (0.64, 0.86); [underlined: Intermediate DP] vs. Western DP; (Ref): 0.68 (0.55, 0.84) | Key confounders accounted for: Parity, Smoking, Age, Pre-pregnancy BMI; Other covariates: Father’s height; Funding: March of Dimes Birth Defects Foundation, Danish National Research Foundation, the European Union, the Pharmacy Foundation, the Egmont Foundation, the Augustinus Foundation and the Health Foundation; Summary: Higher alignment with the intermediate or health conscious DP compared to the Western DP was associated with lower risk of SGA.
Li, 2021^23^; PCS, China, Tongji Maternal and Child Health Cohort; Analytic N=2847; - Age (y): 28.12±3.54; - Race/Ethnicity (%): Han Chinese: 97; - SEP:; - ○ Education (%): ≤9y: 3.5, 10-12y: 13.2, 13-15y: 26.9, ≥16y: 53.9; - ○ Personal income (CNY/mo; %): ≤1000: 0.4, 1001-2999: 7.5, 3000-4999: 33.7, 5000-9999: 39.9, ≥10000: 16.2; - Pre-pregnancy BMI:; - ○ 20.77±2.71; - ○ (%) <18.5: 20.0; 24-0-27.9: 10.0; ≥28.0: 1.7; - Current DM (%): 0.0; - Smoking (%): Before pregnancy: 3.6 | Beans-vegetables DP, Fish-meat-eggs DP, Nutswhole grains DP, Organ-poultry-seafood DP, Rice-wheat-fruits DP (continuous, per 1-unit increase) FFQ at: TM2, before GDM diagnosis; DP Description:; [underlined: Beans-vegetables DP]; Higher intake of root vegetables, mushrooms and algae, melon and solanaceous vegetables, beans and bean products (i.e., soybean, mung bean, soybean milk, bean curd, and so on), leafy and cruciferous vegetables; [underlined: Fish-meat-eggs DP]; Higher intake of red meat, freshwater fishes, eggs; [underlined: Nuts-whole grains DP]; Higher intake of nuts, whole grains, dairy products (i.e., milk, milk powder, and yogurt); [underlined: Organ-poultry-seafood DP]; Higher intake of animal organ and blood, seafood, poultry; [underlined: Rice-wheat-fruits DP]; Higher intake of rice and wheat products, fruits; Outcomes:; - SGA: <10%ile; - LGA: >90%ile | SGA; Logistic regression; OR (95% CI), per 1-unit increase; [underlined: Beans-vegetables DP]: 0.89 (0.78, 1.02); [underlined: Fish-meat-eggs DP]: 0.97 (0.85, 1.10); [underlined: Nuts-whole grains DP]: 0.95 (0.83, 1.08); [underlined: Organ-poultry-seafood DP]: 0.98 (0.87, 1.11); [underlined: Rice-wheat-fruits DP]: 0.97 (0.86, 1.10); LGA; Logistic regression; OR (95% CI); [underlined: Beans-vegetables DP]: 1.04 (0.92, 1.18); [underlined: Fish-meat-eggs DP]: 1.18 (1.04, 1.34), p<0.05; [underlined: Nuts-whole grains DP]: 1.00 (0.88, 1.13); [underlined: Organ-poultry-seafood DP]: 1.07 (0.95, 1.21); [underlined: Rice-wheat-fruits DP]: 1.11 (0.98, 1.26) | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: Physical activity, family history of diabetes, family history of obesity, alcohol habit, GWG, infant sex, TEI, other DP; Funding: National Program on Basic Research Project of China; National Natural Science Foundation of China; Chinese Nutrition Society Nutrition Science Foundation; Summary: Alignment with beans-vegetables DP, fish-meat-eggs DP, nuts-whole grains DP, organ-poultry-seafood DP, or rice-wheat-fruits DP were not associated with risk of SGA.; Greater alignment with fish-meat-eggs DP was associated with higher risk of LGA.; Alignment with beans-vegetables DP, nuts-whole grains DP, organ-poultry-seafood DP, or rice-wheat-fruits DP was not associated with risk of LGA.
Lu, 2016^25^; PCS, China, BIGCS (Born in Guangzhou Cohort Study); Analytic N=6,954; - Age (y): ~29.0±3.3, p=0.001; - Race/Ethnicity (%): Chinese nationality: 100; - SEP: Education (%): ≤Middle school: 8.5; College: 24.5; Undergraduate: 55.0; Postgraduate: 12.1, p<0.001 between DP; - Income (yuan/mo, %): ≤1,500: 9.5; ≥9,001: 15.5, p<0.001 between DP; - Pre-pregnancy BMI: (%): <18.5: 23.6; ≥24: 9.5; - Current HDP (%): Chronic HTN: 0.0; - Current DM (%): T1 or T2 DM: 0.0; - Smoking (%): Passive smoking: 30.6, p<0.001 between DP | Varied DP; Dairy DP; Meats DP; Fruits, nuts, and Cantonese desserts DP & Vegetables DP vs. Cereals, eggs, and Cantonese soups DP; FFQ at: 24-27 GW; DP Description:; [underlined: Varied DP]: Higher intakes of mixed foods, including noodles, bread, root vegetables, melon vegetables, mushrooms, sea vegetables, bean vegetables, processed vegetables, poultry, animal organ meat, fish, other seafood, bean products, yoghurt, sweet beverages, puffed food, confectioneries, and snacks; [underlined: Dairy DP]: Higher intakes of milk products (including fresh milk, pasteurized milk, milk powder, and formula for pregnant women) and lower intakes of whole vegetables; [underlined: Meats DP]: Higher intakes of red and processed meat; [underlined: Fruits, nuts, and Cantonese desserts DP]: Higher intakes of fruits, nuts, and Cantonese desserts; [underlined: Vegetables DP]: Higher intakes of leafy and cruciferous vegetables; [underlined: Cereals, eggs, and Cantonese soups DP]: Higher intakes of rice, pasta, porridge, eggs, and Cantonese soups; Outcomes:; - SGA: <10%ile Guangzhou GA- and sex-specific reference growth curves; - LGA: <90%ile | SGA; Logistic regression; OR (95% CI); Cereals, eggs, and Cantonese soups DP (Ref, n=1026); [underlined: Varied DP] (n=1224): 0.77 (0.57, 1.04); [underlined: Dairy DP] (n=1020): 0.87 (0.63, 1.21); [underlined: Meats DP] (n=1066): 0.95 (0.69, 1.30); [underlined: Fruits, nuts, and Cantonese desserts DP] (n=799): 0.76 (0.53, 1.10); [underlined: Vegetables DP] (n=1383): 0.77 (0.56, 1.05); LGA; Logistic regression; OR (95% CI); Cereals, eggs, and Cantonese soups DP (Ref, n=1026); [underlined: Varied DP] (n=1224): 1.10 (0.85, 1.42); [underlined: Dairy DP] (n=1020): 1.01 (0.75, 1.35); [underlined: Meats DP] (n=1066): 0.75 (0.56, 1.02); [underlined: Fruits, nuts, and Cantonese] [underlined: desserts DP] (n=799): 1.14 (0.84, 1.54); [underlined: Vegetables DP] (n=1383): 1.03 (0.79, 1.36) | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: alcohol drinking during pregnancy, folic acid supplement use; Funding: Guangzhou Science and Technology Bureau; Summary: Compared to the Cereal, eggs, and Cantonese soups DP, none of the other DP were associated with risk of SGA or LGA.
Maldonado, 2022^27^; PCS, United States, MADRES (Maternal and Developmental Risks from Environmental and Social Stressors); Analytic N=465; - Age (y): SRC Q1: 30.3±0.58, SRC Q4: 27.7±0.52, p=0.001; - Race/Ethnicity (%):; - ○ Non-Hispanic and non-Latina: SRC Q1: 17.1, SRC Q4: 30.2, p=0.018; - ○ US-born Hispanic/Latina: SRC Q1: 27.4, SRC Q4: 44.0, p=0.008; - ○ Foreign-born Hispanic/Latina: SRC Q1: 55.6, SRC Q4: 25.9, p<0.001; - SEP:; - ○ Education (%); <HS: SRC Q1: 37.6, SRC Q4: 24.1, p=0.025; HS diploma or equivalent: SRC Q1: 35.0, SRC Q4: 44.0; >HS: SRC Q1: 34.2, SRC Q4: 20.7; - ○ Total household income; <$15k: SRC Q1: 22.2, SRC Q4: 16.4; $15k-29k: SRC Q1: 23.1, SRC Q4: 25.0; >$30k: SRC Q1: 18.0, SRC Q4: 31.0, p=0.019; - Pre-pregnancy BMI: SRC Q1: 29.9 ± 0.67, SRC Q4: 27.6 ± 0.53, p=0.008; - Current DM (%):; - ○ No DM: SRC Q1: 79.5, SRC Q4: 89.7, p=0.030; - ○ GDM: SRC Q1: 8.6, SRC Q4: 8.6; - ○ Preexisting DM: SRC Q1: 12.0, SRC Q4: 1.7, p=0.002; - Smoking (%): During pregnancy: 1.7% | SRC; VOF (quartiles of alignment; per 1 SD); 24 HR at: Third trimester; DP Description:; [underlined: Solid fat, refined grain, and cheese (SRC)]; - Higher intake of milk, cheese, fruit juices, tomatoes, other vegetables, white potatoes, legumes, seafood, refined grains, meat, processed meats, poultry, eggs, soy protein, nuts and seeds, oils, solid fats, added sugar.; - Lower intake of yogurt, citrus, melons, berries, other fruits, dark green vegetables, other red and orange vegetables, other starchy vegetables, whole grains.; [underlined: Vegetables, oils, and fruit (VOF)]; - Higher intake of milk, yogurt, cheese, citrus, melons, berries, other fruits, fruit juices, dark green vegetables, tomatoes, other red and orange vegetables, other vegetables, white potatoes, other starchy vegetables, legumes, seafood, whole grains, meat, processed meats, poultry, eggs, soy protein, nuts and seeds, oils, added sugar.; - Lower intake of refined grains, solid fats.; Outcomes:; - SGA: <10%ile; - LGA: >90 %ile | SGA; Multivariable logistic regression; OR (95% CI); [underlined: SRC]; Q2 vs Q1 (Ref): 0.54 (0.22, 1.33); Q3 vs Q1 (Ref): 0.23 (0.08, 0.72); Q4 vs Q1 (Ref): 0.27 (0.07, 0.99); p trend: 0.046; per 1 SD: 0.90 (0.54, 1.52), p=1.00; [underlined: VOF]; Q2 vs Q1 (Ref): 0.53 (0.22, 1.30); Q3 vs Q1 (Ref): 0.71 (0.30, 1.64); Q4 vs Q1 (Ref): 0.18 (0.06, 0.58); p trend: 0.028; per 1 SD: 0.61 (0.41, 0.90), p=0.029; LGA; Multivariable logistic regression; OR (95% CI); [underlined: SRC]; Q2 vs Q1 (Ref): 1.23 (0.49, 3.09); Q3 vs Q1 (Ref): 1.46 (0.53, 4.02); Q4 vs Q1 (Ref): 1.52 (0.39, 5.84); p trend: 0.176; per 1 SD: 0.79 (0.50, 1.25), p=1.00; [underlined: VOF]; Q2 vs Q1 (Ref): 1.36 (0.51, 3.61); Q3 vs Q1 (Ref): 1.93 (0.74, 4.99); Q4 vs Q1 (Ref): 2.46 (0.89, 6.79); p trend: 0.062; per 1 SD: 1.30 (0.85, 1.98), p=0.060; Sensitivity analyses tested additional inclusion of child sex or PA and household income in the models which did not materially change results. | Key confounders accounted for: Parity, Smoking, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: TEI; Funding: NIEHS; NIMHHD; EPA; Life Course Approach to Developmental Repercussions of Environmental Agents on Metabolic and Respiratory Health; NIH Office of the Director; Summary: Greater alignment with the SRC DP was associated with lower risk of SGA, but was not associated with risk of LGA. Greater alignment with the SRC DP analyzed continuously was not associated with risk of SGA or LGA. Greater alignment with the VOF DP was associated with lower risk of SGA and higher risk of LGA. Greater alignment with the VOF DP analyzed continuously was associated with lower risk of SGA but was not associated with risk of LGA.
Miele, 2021^28^; PCS, Brazil, Preterm SAMBA (Preterm Screening and Metabolomics in Brazil and Auckland); Analytic N =1,165; - Age (%): ≤19: 25.0; >35: 6.7; - Race/Ethnicity (%): Non-White: 60.3; White: 39.7; - SEP:; - ○ Education (%): <12y: 67.9; - ○ Yearly income (%): ≤$12k: 73.9; - ○ Employed (%): 50.2; - BMI at first visit (%): Overweight: 25.7; Obesity: 17.1; - Current HDP (%): PE: 7.5; - Current DM (%): GDM: 14.1 | Obesogenic DP, Intermediate DP, Vegetarian DP, & Protein DP vs. Traditional DP; 24 HR at: 19-21 GW; DP Descriptions:; [underlined: Obesogenic DP]; Higher in ultra-processed and processed foods using NOVA classification (refined carbohydrate; fats; sweets); [underlined: Intermediate DP]; Lower consumption of same food groups as; "Obesogenic DP"; [underlined: Vegetarian DP]; Higher in dairy; fruits; vegetables; [underlined: Protein DP]; Higher in fatty meats; eggs; beans; very low quantity of natural foods (using NOVA classification); [underlined: Traditional DP]; Higher in beans; meats; eggs; natural or minimally processed foods (using NOVA classification); Outcomes:; - SGA: <10%ile adjusted for maternal characteristics (ethnicity, weight, height and parity), GA at birth, and infant sex using the GROW centile calculator | SGA; Multiple logistic regression; OR; Obesogenic DP vs. Traditional DP; (Ref): 0.84, p≥0.05; [underlined: Intermediate DP] vs. Traditional DP; (Ref): 1.25, p≥0.05; Vegetarian DP vs. Traditional DP; (Ref): 1.44, p≥0.05; [underlined: Protein DP] vs. Traditional DP; (Ref): 1.12, p≥0.05 | Key confounders accounted for: Parity, Race and/or ethnicity, Age, SEP, occupation, education not associated with outcome, Pre-pregnancy BMI; Other covariates: Region; Funding: Brazilian National Research Council; Bill and Melinda Gates Foundation; Summary: Alignment with the Obesogenic DP, Intermediate DP, Vegetarian DP, and Protein DP was not associated with risk of SGA when compared to the Traditional DP.
Mikeš, 2022^29^; PCS, Czech Republic, ELSPAC-CZ (European Longitudinal Study of Pregnancy and Childhood); Analytic N=4320; - Age (y): 25±5; - SEP: Education (%): Elementary: 7.5; Secondary school: 74.6; University: 17.4; - Pre-pregnancy BMI:; - ○ 22.0±3.3; - ○ (%): ≤18.5: 7.7; 25-<30:10.2; ≥30: 3.0; - Smoking (%):; - ○ Smoker: 8.5; - ○ Former smoker: 33.3; - ○ Non-smoker: 56.8 | Unhealthy DP, Healthy/traditional DP (continuous by 1 SD increase); FFQ at: 32 GW; DP Description:; [underlined: Unhealthy DP]; Higher intake of fried potatoes, offal, fish and fish products, pizza, doughnuts and omelettes, fried food, poultry, cake and pies, processed meat, pasta, cola drinks, wafers, chocolates and sweets, red meat, sweet drinks.; [underlined: Healthy/traditional DP]; Higher intake of root vegetables, cheese, milk, dairy products, fresh fruits, leafy vegetables, salads, wholemeal bread, boiled potatoes, juice, herbal tea, honey, white bread.; Outcomes:; - SGA: <10%ile | SGA; Logistic regression; OR (95% CI); [underlined: Unhealthy DP]: 1.04 (0.91, 1.19), p=0.590; [underlined: Healthy/traditional DP]: 1.01 (0.90, 1.13), p=0.850 | Key confounders accounted for: Parity, Smoking, Age, SEP, Pre-pregnancy BMI; Other covariates: alcohol consumption, child sex; Funding: Ministry of Education, Youth and Sports; Operational Programme Research, Development and Innovation; EU Horizon 2020 research and innovation programme; Summary: Alignment with an unhealthy DP or a healthy/traditional DP was not associated with risk of SGA.
Okubo, 2012^32^; PCS, Japan, OMCHS (Osaka Maternal and Child Health Study); Exposure N=Meat and Eggs: 326; Wheat products: 303, Comparator N=174; (Meat and eggs DP; Wheat products DP; Rice, fish, & vegetables DP); - Age (y, %): p<0.001: <29: 39.0, 40.9, 27.0; 29–31: 25.5, 28.4, 43.1; ≥32: 35.6, 30.7, 29.9; - SEP:; - ○ Occupation (%): Homemaker: ~71; Outside work: ~29; - ○ Education (y, %), p=0.005; <13: 30.4, 31.0, 21.8; 13-14: 40.8, 46.5, 40.2; ≥15: 28.8, 22.4, 37.9; - ○ Household income (Japanese yen/year, %): <4M: ~28.1; 4-<6M: ~40.4; ≥6M: ~31.5; - Pre-pregnancy BMI: At age 20y: ~20.2 (95% CI: 20, 21); - Smoking (%): p=0.012; - ○ Former: 10.4; 13.5; 13.2; - ○ Current: 14.7; 21.1; 10.3 | Meat and eggs DP; Wheat products DP vs Rice, fish, and vegetables DP; FFQ at: 5-39 GW (mean 18 GW); DP Description:; [underlined: Meat and eggs DP]; Higher intakes of beef & pork, processed meat, chicken, eggs, butter, & dairy products; [underlined: Wheat products DP]; Higher intakes of bread, confectioneries, fruit & vegetable juice, & soft drinks; [underlined: Rice, fish, and vegetables DP]; Higher intakes of rice, potatoes, nuts, pulses, fruits, green & yellow vegetables, white vegetables, mushrooms, seaweeds, Japanese & Chinese tea, fish, shellfish, sea products, miso soup & salt-containing seasoning; Outcomes:; - SGA: <10th%ile of Japanese gestational age- and sex-specific reference growth curves | SGA; Logistic regression; OR (95% CI); [underlined: Meat and eggs DP] vs Rice, fish, and vegetables DP (Ref): 4.32 (0.92, 20.3); [underlined: Wheat products DP] vs Rice, fish, and vegetables DP (Ref): 5.24 (1.13, 24.4) | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, Pre-pregnancy BMI; Other covariates: maternal height, GWG, GW at BL, change in diet in previous 1 month, dietary supplement use, PA level, family structure, season of BL data collection, medical problems in pregnancy, infant sex; Funding: Ministry of Education, Culture, Sports, Science and Technology; Ministry of Health, Labour and Welfare; Japan Society for the Promotion of Science; Summary: Greater alignment with the wheat products DP compared to the rice, fish, and vegetables DP was associated with higher risk of SGA.; The meat and eggs DP compared to the rice, fish, and vegetables DP was not associated with risk of SGA.
Paknahad, 2019^34^; PCS, Iran (Islamic Rep. of), Selseleh County Health Centers; Exposure N=HCLF: 34, HCHF: 55, Comparator N=61; - Age (y): HCLF: 27.67±6.1; HCHF: 27.70±4.1; High fiber: 29.27±5.8; - SEP: Job (%): Homemaker: HCLF: 97.1; HCHF: 96.4; High fiber: 96.7; Employed: HCLF: 2.9; HCHF: 3.6; High fiber: 3.3; - Pre-pregnancy BMI: Baseline BMI: HCLF: 26.2; HCHF: 26.8; High fiber: 25.8; - Current DM (%):; - ○ T1 or T2 DM: 0.0; - ○ GDM: HCLF: 4.0; HCHF: 2.0; High fiber: 0.7 | HCLF DP & HCHF DP vs. High fiber DP; FFQ at: TM1; DP Description:; [underlined: High Carbohydrate-Lower Fat (HCLF) DP]:; High intake of potato; fried potato; flour; egg; cooked carrots; pickles; noodle soup; beans; pomegranate; corn and maize; lentils; low-fat milk; lettuce; and raw carrot; [underlined: High Carbohydrate-Higher Fat (HCHF) DP]:; High intake of pea; soybean; fish; cabbage; cooked spinach; vegetable; high-fat milk; butter; tomato; cucumber; soup; cooked beans; and diluted yogurt; [underlined: High fiber DP]:; High intake of cantaloupe; melon; peach; nectarine; green tomatoes; plums; watermelons; pears; apricots; Outcomes:; - LBW: ≤2500 g; - Macrosomia: >4000 g | LBW; Linear regression; OR (95% CI); [underlined: HCLF] vs. High fiber (Ref): 3.41; (0.57, 21.4), p=0.19; [underlined: HCHF] vs. High fiber (Ref): 3.23; (0.56, 18.57), p=0.18; Macrosomia; Linear regression; OR (95% CI); [underlined: HCLF] vs. High fiber (Ref): 1.03; (0.34, 5.61), p=0.91; [underlined: HCHF] vs. High fiber (Ref): 2.38; (0.17, 32.52), p=0.23 | Key confounders accounted for: Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: disease history, catching diseases, energy intake; Funding: NR; Summary: Alignment with the HCLF DP or the HCHF DP, compared to alignment with the High fiber DP, was not associated with risk of LBW or macrosomia.
Teixeira, 2021^42^; PCS, Brazil, ProcriAr Cohort Study (The Influence of Nutritional Factors and Urban Air Pollutants on Children’s Respiratory Health: A Cohort Study in Pregnant Women); Analytic N=299; - Age (y): Median: 25.9; - SEP (%):; - ○ Education ≥8y: 54.9; - ○ No formal work: 49.8; - ○ Married: 59.9; - Pre-pregnancy BMI: (%) 25-29.9: 31.4; ≥30: 16.7; - Current HDP (%): Excluded due to medical complications during pregnancy; - Current DM (%): 0 chronic disease; - Smoking (%): During pre-pregnancy: 13.1 | DP1, DP2, DP3, & DP4 (quintiles of alignment); FFQ at: 11.1 (10.9, 11.6) GW; DP Description:; [underlined: DP1: ‘Lentils, whole grains and soups’]; - Higher intake of lentils, wheat bread and brown rice, soups, popcorn, cereal ready to eat and oats, white cheese, desserts with fruits and jelly, simple cakes, soya beverages, beef jerky, nuts, crackers, soya sauce, tea (sweetened), beef, stuffed pasta, feijoada, fruits, yogurt (whole milk); - Lower intake of French bread and white rice; [underlined: DP2: ‘Snacks, sandwiches, sweets and soft drinks’]; - Higher intake of processed meats, sandwiches and snacks, sandwich sauces, desserts and sweets, soft drinks, pasta with meat sauce, stuffed pasta, yogurt with flavor, pork and frankfurters, bakery with filling, fried beef and fried chicken, fried egg or omelette, potato salad, with vegetables and mayonnaise, alcoholic beverages, chocolate milk, feijoada, potato or cassava, mozzarella cheese; - Lower intake of yogurt; [underlined: DP3: ‘Seasoned vegetables and lean meats’]; - Higher intake of potato salad, with vegetables and mayonnaise, vegetables, oil (for salad dressing), salt, lean meats and fish, potato or cassava, fruits, French bread and white rice, and unsweetened juices (natural or artificial); [underlined: DP4: ‘Sweetened juices, bread and butter, rice and] [underlined: beans’]; - Higher intake of sweetened juices (natural or artificial), butter or margarine, French bread and white rice, beans, whole milk, yogurt, fried egg or omelette, potato or cassava (fried); - Lower intake of unsweetened juices (natural or artificial), alcoholic beverages; Outcomes:; - SGA: <10%ile based on INTERGROWTH-21st GA-and sex-specific reference growth curves | SGA; Poisson regression, RR (95% CI); [underlined: Lentils, whole grains and soups]; Quintile 2 vs. Quintile 1 (Ref): 1.16; (0.64, 2.12), p=0.62; Quintile 3 vs. Quintile 1 (Ref): 0.82; (0.43, 1.59), p=0.56; Quintile 4 vs. Quintile 1 (Ref): 1.34; (0.79, 2.28), p=0.28; Quintile 5 vs. Quintile 1 (Ref): 1.28; (0.66, 2.48), p=0.46; [underlined: Snacks, sandwiches, sweets and soft drinks]; Quintile 2 vs. Quintile 1 (Ref): 0.91; (0.46, 1.80), p=0.78; Quintile 3 vs. Quintile 1 (Ref): 1.31; (0.69, 2.48), p=0.41; Quintile 4 vs. Quintile 1 (Ref): 0.85; (0.43, 1.67), p=0.63; Quintile 5 vs. Quintile 1 (Ref): 1.92; (1.08, 3.39), p=0.03 p-trend=0.041; [underlined: Seasoned vegetables and lean meats]; Quintile 2 vs. Quintile 1 (Ref): 0.79; (0.41, 1.55), p=0.50; Quintile 3 vs. Quintile 1 (Ref): 0.86; (0.48, 1.53), p=0.61; Quintile 4 vs. Quintile 1 (Ref): 1.46; (0.88, 2.43), p=0.14; Quintile 5 vs. Quintile 1 (Ref): 0.90; (0.48, 1.68), p=0.73; [underlined: Sweetened juices, bread and butter, rice and beans]; Quintile 2 vs. Quintile 1 (Ref): 0.95; (0.55, 1.66), p=0.86; Quintile 3 vs. Quintile 1 (Ref): 0.74; (0.42, 1.30), p=0.29; Quintile 4 vs. Quintile 1 (Ref): 0.69; (0.39, 1.23), p=0.21; Quintile 5 vs. Quintile 1 (Ref): 0.72; (0.39, 1.34), p=0.30 | Key confounders accounted for: Parity, Smoking, Age, SEP, Pre-pregnancy BMI, Current HDP; Other covariates: Marriage status; Other 3 DP; Funding: Sao Paulo Research Foundation; National Council for Scientific and Technological Development; Summary: Greater alignment with the Snacks, sandwiches, sweets and soft drinks DP was associated with risk of SGA.; Alignment with the 3 other DP was not associated with risk of SGA.
Yamashita, 2022^44^; PCS, Japan, TMM BirThree Cohort Study (Tohoku Medical Megabank Project Birth and Three-Generation Cohort Study); Analytic N=17,728; - Age (y): <25: 7.2, 25-29: 25.3, 30-34: 37.1, ≥35: 30.3; - SEP (%):; - ○ Education: ≤HS graduate or above: 18.7; Missing: 35.7; - ○ Annual household income, Japanese yen/y: <4M: 34.5, 4M-<6M: 31.2, ≥6M: 29.8; - Pre-pregnancy BMI: 21.6±3.4; - Current HDP (%): HDP: 3.9; - Current DM (%): GDM: 2.3; - Smoking (%):; - ○ Never: 60.3; - ○ Quit before pregnancy: 23.0; - ○ Quit after noticing pregnancy: 14.0; - ○ Current: 2.3 | PCA1 - pre- to early pregnancy, PCA1- early to midpregnancy, PCA2 - pre- to early pregnancy, PCA2-early to mid-pregnancy (quartiles of alignment) FFQ at: 20.6 ± 7.8 GW, 28.5 ± 5.8 GW; DP Description:; [underlined: PCA1 - pre- to early pregnancy]; - Higher intake of pulses, vegetables, fruits, mushroom, fish and shellfish.; - Lower intake of milk and dairy products.; [underlined: PCA1 - early to mid-pregnancy]; - Higher intake of pulses, vegetables, fruits, mushroom, fish and shellfish.; - Lower intake of milk and dairy products, alcohol beverage.; [underlined: PCA2 - pre- to early pregnancy]; - Higher intake of vegetables, eggs, milk and dairy products.; - Lower intake of cereals, meat.; [underlined: PCA2 - early to mid-pregnancy]; - Higher intake of pulses, vegetables, eggs, milk and dairy products.; - Lower intake of cereals, meat.; Outcomes:; - SGA: <10%ile based on Japan Pediatric Society standard | SGA; Logistic regression; OR (95% CI); [underlined: PCA1 - pre- to early pregnancy]; Q2 vs Q1 (Ref): 0.88 (0.74, 1.05); Q3 vs Q1 (Ref): 0.95 (0.80, 1.13); Q4 vs Q1 (Ref): 1.02 (0.86, 1.21); p trend: 0.63; [underlined: PCA1 - early to mid-pregnancy]; Q2 vs Q1 (Ref): 1.03 (0.86, 1.22); Q3 vs Q1 (Ref): 1.15 (0.97, 1.37); Q4 vs Q1 (Ref): 0.99 (0.83, 1.19); p trend: 0.72; [underlined: PCA2 - pre- to early pregnancy]; Q2 vs Q1 (Ref): 1.04 (0.88, 1.23); Q3 vs Q1 (Ref): 0.79 (0.66, 0.95); Q4 vs Q1 (Ref): 0.95 (0.80, 1.13); p trend: 0.15; [underlined: PCA2 - early to mid-pregnancy]; Q2 vs Q1 (Ref): 0.94 (0.79, 1.12); Q3 vs Q1 (Ref): 0.95 (0.80, 1.12); Q4 vs Q1 (Ref): 0.86 (0.72, 1.03); p trend: 0.11 | Key confounders accounted for: Smoking, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: alcohol drinking, folic acid supplement consumption during early pregnancy, GWG; Funding: Japan Agency for Medical Research and Development; Summary: Alignment with the PCA1 pattern and the PCA2 pattern during pre- and early pregnancy were not associated with risk of SGA, with the exception of comparisons between Q3 and Q1 for PCA2.; Alignment with the PCA1 and PCA2 patterns during early to mid-pregnancy were not associated with risk of SGA.
Yisahak, 2021^46^; PCS, United States, NICHD Fetal Growth Studies-Singletons; Analytic N=1,948; - Age (y):; - ○ PCA pattern 1: Q1: 29.5±5.4, Q4: 25.4±5.4, p<0.001; - ○ Other DPs: Q1: ~26, Q4: ~30, p<0.001; - Race/Ethnicity (%):; - ○ PCA pattern 1 (%), p<0.001: NHW: Q1: 16, Q4: 13; NHB: Q1: 19, Q4: 50; Hispanic: Q1: 29, Q4: 29; AAPI: Q1: 36, Q4: 8; - ○ Other DPs (%), p<0.001: NHW: Q1: ~15, Q4: ~28; NHB: Q1: ~49, Q4: ~18; Hispanic: Q1: ~26, Q4: ~26; AAPI: Q1: ~10, Q4: ~29; - SEP:; - PCA pattern 1 (%):; - ○ Education <HS: Q1: 13, Q4: 15; HS or equivalent: Q1: 15, Q4: 29; Postgraduate: Q1: 19, Q4: 9, p<0.001; - ○ Income ($) <30k: Q1: 28, Q4: 50; ≥100k: Q1: 24, Q4: 14, p<0.001; - ○ Full-time school or work: Q1: 65, Q4: 68; - ○ Insurance (private/managed care): Q1: 66, Q4: 43, p<0.001; - Other DPs (%):; - ○ Education <HS: Q1: ~15, Q4: ~9; HS or equivalent: Q1: ~27, Q4: ~13; Postgraduate: Q1: ~7, Q4: ~28, p<0.001; - ○ Income ($) <30k: Q1: 47, Q4: 23; ≥100k: Q1: 11, Q4: 38, p<0.001; - ○ Full-time school or work: Q1: 67, Q4: 71; - ○ Insurance (private/managed care): Q1: 48, Q4: 72, p<0.001; - Pre-pregnancy BMI: Q1: ~26.1, Q4: 24.2, p<0.001; - Smoking (%): With obesity: n=17, Without obesity: 0.0 | PCA Patterns 1 and 3 (quartiles of alignment); FFQ at: 8-13 GW; DP Description:; [underlined: PCA pattern 1]; - Higher intake of solid fat, nonwhole grains, white potatoes, meat (from beef, pork, veal, lamb, and game), cheese.; [underlined: PCA pattern 2]; - Higher intake of other vegetables (not potatoes, starchy, orange, or dark-green vegetables), dark-green vegetables, orange vegetables, seafood high in omega-3 fatty acids, seafood low in omega-3 fatty acids.; Outcomes:; - SGA <10%ile, by sex-specific U.S. reference (Duryea); - LGA ≥90%ile; - LBW <2500g; - Macrosomia ≥4000g | SGA; Logistic regression; OR (95% CI); [underlined: PCA pattern 1]; Q2 vs Q1 (Ref): 1.56 (0.93, 2.67); Q3 vs Q1 (Ref): 1.37 (0.76, 2.48); Q4 vs Q1 (Ref): 1.24 (0.53, 2.86); p trend: 0.81; [underlined: PCA pattern 2]; Q2 vs Q1 (Ref): 0.70 (0.42, 1.19); Q3 vs Q1 (Ref): 0.72 (0.41, 1.25); Q4 vs Q1 (Ref): 0.66 (0.36, 1.21); p trend: 0.25; LGA; Logistic regression; OR (95% CI); [underlined: PCA pattern 1]; Q2 vs Q1 (Ref): 0.91 (0.53, 1.56); Q3 vs Q1 (Ref): 0.92 (0.50, 1.68); Q4 vs Q1 (Ref): 0.71 (0.28, 1.85); p trend: 0.51; [underlined: PCA pattern 2]; Q2 vs Q1 (Ref): 0.81 (0.46, 1.42); Q3 vs Q1 (Ref): 1.12 (0.64, 1.94); Q4 vs Q1 (Ref): 0.97 (0.50, 1.88); p trend: 0.88; LBW; Logistic regression; OR (95% CI); [underlined: PCA pattern 1]; Q2 vs Q1 (Ref): 1.07 (0.49, 2.34); Q3 vs Q1 (Ref): 1.47 (0.67, 3.20); Q4 vs Q1 (Ref): 1.11 (0.34, 3.46); p trend: 0.85; [underlined: PCA pattern 2]; Q2 vs Q1 (Ref): 1.08 (0.58, 2.02); Q3 vs Q1 (Ref): 0.79 (0.37, 1.67); Q4 vs Q1 (Ref): 0.64 (0.29, 1.41); p trend: 0.19; Macrosomia; Logistic regression; OR (95% CI); [underlined: PCA pattern 1]; Q2 vs Q1 (Ref): 1.39 (0.78, 2.48); Q3 vs Q1 (Ref): 1.31 (0.66, 2.61); Q4 vs Q1 (Ref): 1.35 (0.46, 3.95); p trend: 0.64; [underlined: PCA pattern 2]; Q2 vs Q1 (Ref): 0.95 (0.53, 1.70); Q3 vs Q1 (Ref): 1.17 (0.65, 2.12); Q4 vs Q1 (Ref): 1.03 (0.52, 2.03); p trend: 0.87" | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Age, SEP, income, current job/student status, insurance coverage, Pre-pregnancy BMI; Other covariates: height, marital status, study site, infant sex, total weekly physical activity, total daily energy intake; Funding: NICHD; American Recovery and Reinvestment Act; Summary: Alignment with PCA pattern 1, PCA pattern 2, AHEI-2010, and DASH were not associated with risk of LBW, macrosomia, LGA, or SGA.
Zhang, 2023^47^; PCS, China, TAWS (Taicang and Wuqiang Mother–Child Cohort Study); Analytic N=911; - Age (y): Median (IQR): 28.0 (25.0, 30.0); - SEP: Education (%): ≤Primary school: 67.8, ≥HS: 32.2; - Pre-pregnancy BMI:; - ○ Underweight (%): 6.2; - ○ Overweight (%): 30.5; - ○ Obesity (%): 12.3; - Current HDP (%): HDP: 2.0; - Current DM (%): GDM: 6.5 | Cereals-vegetables-fruits DP, Vegetables-poultry-aquatic products DP, Milk-meat-eggs DP, Nuts-aquatic products-snacks DP (tertiles of alignment); FFQ at: TM1; DP Description:; [underlined: Cereals-vegetables-fruits DP]; Higher intake of cereals, tubers and their products, dark vegetables, light vegetables, fruits; [underlined: Vegetables-poultry-aquatic products DP]; Higher intake of dark vegetables, light vegetables, mushroom and algae, poultry, meat products, fish, shrimp, and other aquatic products; [underlined: Milk-meat-eggs DP]; Higher intake of milk, red meat (pork), meat products, eggs; [underlined: Nuts-aquatic products-snacks DP]; Fish, shrimp, and other aquatic products, eggs, bread, biscuits, chocolate, and other snacks, nuts; Outcomes:; - LGA: >90%ile, by GA- and sex-specific national growth standards; - Macrosomia: ≥4000 g | LGA; Logistic regression; OR (95% CI); [underlined: Cereals-vegetables-fruits DP]; T2 vs T1 (Ref): 1.526 (0.889, 2.62), p=0.125; T3 vs T1 (Ref): 1.578 (0.876, 2.845), p=0.129; [underlined: Vegetables-poultry-aquatic] [underlined: products DP]; T2 vs T1 (Ref): 0.793 (0.465, 1.352), p=0.394; T3 vs T1 (Ref): 1.053 (0.569, 1.948), p=0.870; [underlined: Milk-meat-eggs DP]; T2 vs T1 (Ref): 1.466 (0.914, 2.35), p=0.113; T3 vs T1 (Ref): 1.219 (0.724, 2.055), p=0.456; [underlined: Nuts-aquatic products-snacks DP]; T2 vs T1 (Ref): 0.901 (0.565, 1.437), p=0.662; T3 vs T1 (Ref): 0.645 (0.38, 1.095), p=0.105; LGA; [underlined: By PPBMI]; [underlined: Cereals-vegetables-fruits DP]; Healthy weight (n=521); T2 vs T1 (Ref): 1.616 (0.732, 3.566), p=0.235; T3 vs T2 (Ref): 1.113 (0.461, 2.682), p=0.812; Overweight and obesity (n=390); T2 vs T1 (Ref): 1.501 (0.705, 3.193), p=0.292; T3 vs T1 (Ref): 2.353 (1.010, 5.480), p=0.047; [underlined: Poultry-vegetables-aquatic products DP]; Healthy weight (n=521); T2 vs T1 (Ref): 1.019 (0.453, 2.291), p=0.964; T3 vs T1 (Ref): 1.297 (0.502, 3.353), p=0.592; Overweight and obesity (n=390); T2 vs T1 (Ref): 0.560 (0.266, 1.179), p=0.127; T3 vs T1 (Ref): 0.868 (0.364, 2.069), p=0.750; [underlined: Milk-meat-eggs DP]; Healthy weight (n=521); T2 vs T1 (Ref): 1.224 (0.585, 2.562), p=0.592; T3 vs T1 (Ref): 1.130 (0.508, 2.510), p=0.765; Overweight and obesity (n=390); T2 vs T1 (Ref): 1.681 (0.884, 3.197), p=0.113; T3 vs T1 (Ref): 1.224 (0.594, 2.521), p=0.584; LGA; [underlined: By PPBMI]; [underlined: Nuts-aquatic products-snacks DP]; Healthy weight (n=521); T2 vs T1 (Ref); 1.231 (0.606, 2.501), p=0.565; T3 vs T1 (Ref): 0.808 (0.365, 1.791), p=0.600; Overweight and obesity (n=390); T2 vs T1 (Ref): 0.695 (0.367, 1.317), p=0.265; T3 vs T1 (Ref): 0.542 (0.260, 1.131), p=0.103; Macrosomia; Logistic regression; OR (95% CI); [underlined: Cereals-vegetables-fruits DP]; T2 vs T1 (Ref): 1.981 (0.976, 4.022), p=0.058; T3 vs T1 (Ref): 2.220 (1.018, 4.843), p=0.045; [underlined: Vegetables-poultry-aquatic products DP]; T2 vs T1 (Ref): 0.908 (0.455, 1.811), p=0.783; T3 vs T1 (Ref): 0.874 (0.382, 2.002), p=0.750; [underlined: Milk-meat-eggs DP]; T2 vs T1 (Ref): 0.984 (0.539, 1.796), p=0.958; T3 vs T1 (Ref): 1.113 (0.576, 2.153), p=0.750; [underlined: Nuts-aquatic products-snacks DP]; T2 vs T1 (Ref): 0.718 (0.403, 1.278), p=0.260; T3 vs T1 (Ref): 0.357 (0.175, 0.725), p=0.004 | Key confounders accounted for: Parity, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: other DP, PA level; Funding: National Institute for Nutrition and Health; Summary: Higher alignment with the cereals-vegetables-fruit DP was associated with higher risk of macrosomia and, among those with prepregnancy overweight/obesity, higher risk of LGA. Higher alignment with the nuts-aquatic products-snacks DP was associated with lower risk of macrosomia.; Alignment with the vegetables- poultry-aquatic products DP or the milk-meat-eggs DP was not associated with risk of macrosomia or LGA.
Zulyniak, 2017^49^; PCS, Canada, NutriGen Alliance: CHILD (Canadian Healthy Infant Longitudinal Development), FAMILY (Family Atherosclerosis Monitoring In early life), START (SouTh Asian birth cohort), ABC (Aboriginal Birth Cohort); Analytic N=White Europeans: 2,367, South Asians: 884; - Age (y): 31.6±4.7; - Race/Ethnicity (%): White European: 59; South Asian: 22; East/SouthEast Asian: 8; Aboriginal: 5; Other ethnicity: 4; African: 2; - SEP:; - ○ Postsecondary education (%): 85.1; - ○ Household income ≥$60k (%): 77.2; - Pre-pregnancy BMI: 24.7±4.8; - Current DM (%): GDM: 11.3; - Smoking (%):; - ○ Never: 77.1; - ○ Quit before pregnancy: 16.2; - ○ Quit during pregnancy: 3.6; - ○ Currently smoking: 3.1 | Plant-based DP (continuous, per 1 unit increase) FFQ at: 24-28 GW; DP Description:; - Higher intake of low fat dairy, fermented dairy, legumes, fresh seasonings, vegetable medley, other vegetables, whole grains, non-meat dishes, tea.; - Lower intake of meat.; Outcomes:; - SGA: <10%ile, by sex- and ethnic-specific birth weight cut points; - LGA: ≥90%ile | SGA; [underlined: White Europeans]: ~50% increase in odds with 1-unit increase in plant-based DP; [underlined: South Asians]: non-significant reduction in odds with 1-unit increase in plant-based DP, p=0.428; LGA; [underlined: White Europeans]: ~30% decrease in odds with 1-unit increase in plant-based DP; [underlined: South Asians]: non-significant increase in odds with 1-unit increase in plant-based DP, p=0.249 | Key confounders accounted for: Parity, Smoking, Race and/or ethnicity, Pre-pregnancy BMI; Other covariates: GA, infant sex; Funding: CIHR; ICMR/CIHR; HSF Canada; AllerGen NCE Inc; South Asian Nework Supporting Awareness and Research; Summary: Higher alignment with a plant-based DP was associated with higher risk of SGA and lower risk of LGA among White Europeans.; Alignment with a plant-based DP was not associated with risk of SGA or LGA among South Asians, but results trended to lower risk of SGA and higher risk of LGA.
Reduced Rank Regression
Alves-Santos, 2019^1^; PCS, Brazil, Rio de Janeiro Federal University; Analytic N=189; - Age (y): 26.7±5.5; - SEP:; - ○ Per capita family income (US dollars/mo): 524.4±370.0; - ○ Education (y): 8.7±2.9; - Pre-pregnancy BMI:; - ○ 25.13±4.5; - ○ ≥25 (%): 42.0; - Current DM (%): Free from chronic disease: 100; - Smoking (%): 6.2 | Fast food and Candies DP; Vegetables and Dairy DP; Beans, Bread, and Fat DP (tertiles of alignment: High, Medium vs Low); FFQ at: TM1; DP Description:; [underlined: Fast Food and Candies DP]; High intakes of fast food and snacks; cakes, cookies, or crackers; and candies or desserts; low intakes of rice, beans, vegetables spices, and green vegetables or legumes; [underlined: Vegetables and Dairy DP]; High intakes of green vegetables or legumes, dairy products, fish, tea, fruits or fruit juices, and candies or desserts; low intakes of bread, sweetened and diet soda, and table sugar; [underlined: Beans, Bread, and Fat DP]; High intakes of beans; cakes, or cookies, or crackers; bread and fats used as spreads; low intakes of fish, fruit or fruit juices, and noodles, pasta, roots, or tubers; Outcomes:; - LGA: >90%ile based on International Fetal and Newborn Growth Consortium for the 21^st^ Century. | LGA; Multiple logistic regression; OR (95% CI); [underlined: Fast Food and Candies DP]; Medium vs. Low (Ref): 4.23 (1.23, 14.54), p=0.022; High vs. Low (Ref): 4.38 (1.32, 14.48), p=0.015; [underlined: Vegetables and Dairy DP]; Medium vs. Low (Ref): 0.63 (0.21, 1.94), p=0.428; High vs. Low (Ref): 1.90 (0.72, 5.02), p=0.195; [underlined: Beans, Bread, and Fat DP]; Medium vs. Low (Ref): 0.64 (0.25, 1.63), p=0.354; High vs. Low (Ref): 0.46 (0.17, 1.27), p=0.136 | Key confounders accounted for: Smoking, Age, SEP; Other covariates: Alcohol consumption; TM1 leisure physical activity; Funding: Carlos Chagas Filho Research Foundation from the State of Rio de Janeiro; Summary: Medium and high alignment with the Fast Food and Candies DP was associated with greater risk of LGA when compared to low alignment. There was no association between alignment with the Vegetables and Dairy DP or the Beans, Bread, and Fat DP and risk of LGA.
Hwang, 2022^20^; PCS, Korea, MOCEH (Korean Mothers and Children’s Environmental Health study); Analytic N=888; (Pattern 1 Q1, Q4); - Age (y): 29.9±3.9, 30.5±3.5; - SEP:; - ○ Education (%): ≤HS: 26.3, 26.3; ≤University: 21.8, 16.6; ≥Graduate school: 49.5, 56.1; - ○ Family income (%), $/mo: <2k: 30.1, 27.0; 2k-4k: 51.6, 49.5; >4k: 15.2, 21.1; - Pre-pregnancy BMI: 21.1±3.1, 21.5±3.2; - Current HDP (%): Pregnancy complications (HTN): 0.0; - Current DM (%): Pregnancy complications (DM): 0.0 | Pattern 1, Pattern 2, Pattern 3 (quartiles of alignment) FFQ at: 12-28 GW; DP Description:; [underlined: Pattern 1]; - Higher intakes of grains, green/yellow and light-colored vegetables, kimchi, legumes, fruits, meat, eggs, fish, seaweeds, tofu/soymilk, yogurt, nuts.; [underlined: Pattern 2]; - Higher intakes of green/yellow and light-colored vegetables, kimchi, seaweed.; - Lower intakes of white rice, poultry, meat, red meat by-products.; [underlined: Pattern 3]; - Higher intakes of grains, milk, yogurt.; - Lower intakes of rice cake, legumes, snacks, bony fish, tofu/soy milk.; Outcomes:; - SGA: <10%ile based on sex-specific reference growth curves in Korean singleton infants | SGA; Logistic regression; OR (95% CI); [underlined: Pattern 1]; Q2 vs Q1 (Ref): 0.23 (0.06, 0.92); Q3 vs Q1 (Ref): 0.43 (0.20, 0.95); Q4 vs Q1 (Ref): 0.36 (0.14, 0.94); p trend: 0.048; [underlined: Pattern 2]; Q2 vs Q1 (Ref): 1.12 (0.54, 2.32); Q3 vs Q1 (Ref): 0.58 (0.18, 1.72); Q4 vs Q1 (Ref): 0.78 (0.45, 1.91); p trend: 0.359; [underlined: Pattern 3]; Q2 vs Q1 (Ref): 0.63 (0.45, 1.33); Q3 vs Q1 (Ref): 0.86 (0.72, 1.11); Q4 vs Q1 (Ref): 0.88 (0.36, 1.68); p trend: 0.056 | Key confounders accounted for: Parity, Smoking, Age, SEP, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: maternal energy intake (log-transformed); Funding: Ministry of Science & ICT, Republic of Korea; Summary: Alignment with Pattern 1 was associated with lower risk of SGA. Alignment with Pattern 3 trended toward an association of lower risk of SGA but was not statistically significant. Pattern 2 was not associated with risk of SGA.
Lecorguillé, 2020^22^; PCS, France, EDEN Mother-Child Study; Analytic N=1638; - Age (y): 29.7±4.9; - SEP:; - ○ Education (%): Lower secondary school: 25.9, Upper secondary school: 17.9, Post-secondary: 22.6, Tertiary: 33.6; - ○ Employment status (%): Employed: 76.6, Student: 2.6, Staying at home: 20.7; - ○ Monthly household income, Euros (%): <1,501: 15.1, 1,501-2,300: 28.4, 2,301-3,000: 26.9, >3,000: 29.6; - Pre-pregnancy BMI (%): Underweight: 8.3; Overweight: 18; Obesity: 7.6; - Current DM (%): Diabetes before pregnancy: 0.0; - Smoking (%): During pregnancy: No: 74.2, 1-9/d: 21.2, ≥10/d: 4.6 | Varied and balanced DP, Vegetarian tendency DP, Bread and starchy food DP (continuous, per 1 SD increase); FFQ at: <28 GW (~15 GW); DP Description:; [underlined: Varied and balanced DP]; - Higher intake of low-fat milk, other vegetables, fish, meat, chicory, leek, cabbage, eggs and egg dishes, cereals, broccoli, liver.; - Lower intake of snacks and confectionary, sugar-sweetened beverages.; [underlined: Vegetarian tendency DP]; - Higher intake of other vegetables, chicory, cereals, fruits, bread.; - Lower intake of meat, liver.; [underlined: Bread and starchy food DP]; - Higher intake of bread, rice, pasta, and others, sandwich.; - Lower intake of low-fat milk, fruits, fruit juice, sugar-sweetened beverages.; Outcomes:; - SGA: <10%ile; - LGA: >90%ile | SGA; Logistic regression; OR (95% CI); [underlined: Varied and balanced]: 1.00 (0.86, 1.16); [underlined: Vegetarian tendency]: 1.02 (0.87, 1.21); [underlined: Bread and starchy food]: 0.83 (0.70, 0.99); LGA; Logistic regression; OR (95% CI); [underlined: Varied and balanced]: 1.19 (1.02, 1.39); [underlined: Vegetarian tendency]: 0.97 (0.81, 1.16); [underlined: Bread and starchy food]: 1.00 (0.82, 1.23) | Key confounders accounted for: Parity, Smoking, Age, SEP, employment status, monthly household income, Pre-pregnancy BMI, DM in current pregnancy Other covariates: center, vitamin supplementation, infant sex; Funding: Foundation for Medical Research; National Agency for Research; National Institute for Research in Public Health; French Ministry of Health; French Ministry of Research; INSERM Bone and Joint Diseases National Research; Human Nutrition National Research Programs; Paris-Sud University; Nestle; Fench National Institute for Population Health Surveillance; French National Institute for Health Education; EU FP7 Programs; Diabetes National Research Program; French Agency for Environmental Health Safety; Mutuelle Generale de l’Education Nationale; French National Agency for Food Security; French-Speaking Association for the Study of Diabetes and Metabolism; Summary: Alignment with a bread and starchy food DP was associated with lower risk of SGA but not risk of LGA. Alignment with a varied and balanced DP was associated with a higher risk of LGA but not with risk of SGA. Alignment with a vegetarian tendency DP was not associated with risk of SGA or LGA.
Yamashita, 2022^44^; PCS, Japan, TMM BirThree Cohort Study (Tohoku Medical Megabank Project Birth and Three-Generation Cohort Study); Analytic N=17,728; - Age (y): <25: 7.2, 25-29: 25.3, 30-34: 37.1, ≥35: 30.3; - SEP (%):; - ○ Education: ≤HS graduate: 20.7, College graduate: 24.9, University graduate or above: 18.7; Missing: 35.7; - ○ Annual household income, Japanese yen/y: <4M: 34.5, 4M-<6M: 31.2, ≥6M: 29.8; - Pre-pregnancy BMI: 21.6±3.4; - Current HDP (%): HDP: 3.9; - Current DM (%): GDM: 2.3; - Smoking (%):; - ○ Never: 60.3; - ○ Quit before pregnancy: 23.0; - ○ Quit after noticing pregnancy: 14.0; - ○ Current: 2.3 | RRR - pre- to early pregnancy, RRR - early to midpregnancy (quartiles of alignment) FFQ at: 20.6 ± 7.8 GW, 28.5 ± 5.8 GW; DP Description:; [underlined: RRR - pre- to early pregnancy]; - Higher intake of cereals, fruits.; - Lower intake of alcohol beverage, non-alcohol beverage.; [underlined: RRR - early to mid-pregnancy]; - Higher intake of cereals, fruits, milk and dairy products.; - Lower intake of alcohol beverage, non-alcohol beverage.; Outcomes:; - SGA: <10%ile | SGA; Logistic regression; OR (95% CI); [underlined: RRR - pre- to early pregnancy]; Q2 vs Q1 (Ref): 0.88 (0.75, 1.05); Q3 vs Q1 (Ref): 0.81 (0.68, 0.96); Q4 vs Q1 (Ref): 0.83 (0.69, 0.99); p trend: 0.02; [underlined: RRR - early to mid-pregnancy]; Q2 vs Q1 (Ref): 0.97 (0.82, 1.15); Q3 vs Q1 (Ref): 0.87 (0.73, 1.03); Q4 vs Q1 (Ref): 0.85 (0.71, 1.02); p trend: 0.04 | Key confounders accounted for: Smoking, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy Other covariates: alcohol drinking, folic acid supplement consumption during early pregnancy, GWG; Funding: Japan Agency for Medical Research and Development; Summary: Alignment with the RRR pattern during pre- to early pregnancy was associated with lower risk of SGA. Alignment with the RRR pattern during early to mid-pregnancy was associated with lower risk of SGA but no comparisons between any quartiles reached statistical significance.
Other
Yamashita, 2022^44^; PCS, Japan, TMM BirThree Cohort Study (Tohoku Medical Megabank Project Birth and Three-Generation Cohort Study); Analytic N=17,728; - Age (y): <25: 7.2, 25-29: 25.3, 30-34: 37.1, ≥35: 30.3; - SEP (%):; - ○ Education: ≤HS graduate: 20.7, College graduate: 24.9, University graduate or above: 18.7; Missing: 35.7; - ○ Annual household income, Japanese yen/y: <4M: 34.5, 4M-<6M: 31.2, ≥6M: 29.8; - Pre-pregnancy BMI: 21.6±3.4; - Current HDP (%): HDP: 3.9; - Current DM (%): GDM: 2.3; - Smoking (%):; - ○ Never: 60.3; - ○ Quit before pregnancy: 23.0; - ○ Quit after noticing pregnancy: 14.0; - ○ Current: 2.3 | PLS - pre- to early pregnancy, PLS- early to mid-pregnancy (quartiles of alignment); FFQ at: 20.6 ± 7.8 GW, 28.5 ± 5.8 GW; DP Description:; [underlined: PLS - pre- to early pregnancy]; - Higher intake of cereals, fruits.; - Lower intake of alcohol beverage, non-alcohol beverage.; [underlined: PLS - early to mid-pregnancy]; - Higher intake of cereals, fruits, mushroom, milk and dairy products.; - Lower intake of alcohol beverage, non-alcohol beverage.; Outcomes:; - SGA: <10%ile | SGA; Logistic regression; OR (95% CI); [underlined: PLS - pre- to early pregnancy]; Q2 vs Q1 (Ref): 0.82 (0.69, 0.98); Q3 vs Q1 (Ref): 0.78 (0.66, 0.93); Q4 vs Q1 (Ref): 0.77 (0.64, 0.92); p trend: 0.003; [underlined: PLS - early to mid-pregnancy]; Q2 vs Q1 (Ref): 0.83 (0.70, 0.98); Q3 vs Q1 (Ref): 0.76 (0.64, 0.90); Q4 vs Q1 (Ref): 0.76 (0.64, 0.91); p trend: 0.001 | Key confounders accounted for: Smoking, Age, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: alcohol drinking, folic acid supplement consumption during early pregnancy, GWG; Funding: Japan Agency for Medical Research and Development; Summary: Alignment with PLS pattern during pre- to early pregnancy was associated with lower risk of SGA. Alignment with the PLS pattern during early to mid-pregnancy was associated with lower risk of SGA.

a Abbreviations: %ile: percentile; $#k: # thousands of dollars; #M: million; 24 HR: 24 hour recall; ABC: Aboriginal Birth Cohort; AGA: appropriate for gestational age; AHEI: Alternate Healthy Eating Index; AHEI-P: Alternate Healthy Eating Index for Pregnancy; aMED: alternative Mediterranean diet; BMI: body mass index; BW: birth weight; CG: control group; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DASH: Dietary Approaches to Stop Hypertension; DHA: docosahexaenoic acid; DM: diabetes mellitus; DP: dietary pattern(s); EPA: eicosapentaenoic acid; EVOO: extra virgin olive oil; FFQ: food frequency questionnaire; FIGO: International Federation of Gynecology and Obstetrics; g: gram(s); GDM: gestational diabetes mellitus; GHTN: gestational hypertension; GW: gestational weeks; GWG: gestational weight gain; h: hour(s); HDP: hypertensive disorders of pregnancy; HTN: hypertension; HS: high school; IG: intervention group; INTERGROWTH-21^st^: International Fetal and Newborn Growth Consortium for the 21^st^ Centruy; IQDAG: Diet Quality Index Adapted for Pregnant Women; IQR: interquartile range; ITT: intention-to-treat; kg: kilogram(s); kcal: kilocalorie(s); L: liter; LBW: low birth weight; LGA: large for gestational age; LI: lifestyle intervention; M: million(s); MD: Mediterranean Diet; MDD: Minimum dietary diversity; MDQS: Maternal Diet Quality Score; MEDAS: Mediterranean Diet Adherence Screener; MedDiet: Mediterranean diet; mg: milligram(s); min: minute(s); mL: milliliter; mo: month; MUFA: monounsaturated fatty acid; N: sample size; NH: non-Hispanic; NHB: non-Hispanic Black; NHW: non-Hispanic White; NIH: National Institutes of Health; NICHD: National Institute of Child Health and Development; NND: New Nordic Diet; NOK: Norwegian Krone; NR: not reported; OMNI: Optimal Macronutrient Intake; OR: odds ratio; PA: physical activity; PCA: principal component analysis; PCS: prospective cohort study; PE: preeclampsia; PLS: partial least squares; PP: per-protocol; PPBMI: pre-pregnancy BMI; PTB: preterm birth; PUFA: polyunsaturated fatty acid; Q#: quartile; RCT: randomized controlled trial; Ref: reference; RR: relative risk; RRR: reduced rank regression; SC: standard care; SD: standard deviation; SEIFA IRSD: Socio-economic Index for Areas—Index of Relative Socio-economic Disadvantage; SEP: socioeconomic position; SES: socioeconomic status; SFA: saturated fatty acid; SGA: small for gestational age; SSB: sugar-sweetened beverage(s); svg: serving(s); T#: tertile; T1 or T2 DM: Type 1 or Type 2 DM; TEI: total energy intake; TG: triglyceride; UC: usual care; ug: microgram(s); U.K.: United Kingdom; vs: versus; wk: week(s); y: year(s)

Table 9 Risk of bias for randomized controlled trials examining dietary patterns consumed during pregnancy and birth weight^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Al Wattar, 2019 ^51^ | LOW | LOW | LOW | LOW | LOW | LOW
Assaf-Balut, 2017 ^52^ | LOW | HIGH | LOW | LOW | HIGH | HIGH
Assaf-Balut, 2019 ^53^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | HIGH
Crovetto, 2021 ^54^ | LOW | HIGH | LOW | LOW | SOME CONCERNS | HIGH
Dodd, 2019 ^55^ | LOW | LOW | LOW | LOW | LOW | LOW
Gallagher, 2018 ^56^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Khoury, 2005 ^57^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Melero, 2020 ^58^ | LOW | HIGH | LOW | LOW | LOW | HIGH
Van Horn, 2018 ^59^ | LOW | LOW | LOW | LOW | LOW | LOW
Zhao, 2022 ^60^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898 31462531 .

Table 10 Risk of bias for randomized controlled trials examining dietary patterns consumed during pregnancy and birth weight^a^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Melero, 2020 ^58^ | SERIOUS | LOW | SERIOUS | SERIOUS | LOW | LOW | MODERATE | SERIOUS

a Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i) ( Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 11 Risk of bias for observational studies examining dietary patterns consumed during pregnancy and birth weight^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Alves-Santos, 2019 ^1^ | HIGH | LOW | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Ancira-Moreno, 2020 ^50^ | HIGH | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Barchitta, 2023 ^2^ | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Berube, 2023 ^3^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Bodnar, 2024 ^4^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Chatzi, 2012 ^5^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Chen, 2021 ^6^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Chia, 2016 ^7^ | HIGH | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
de Seymour, 2022 ^8^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Díaz-López, 2022 ^9^ | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Emond, 2018 ^10^ | LOW | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Englund-Ogge, 2019 ^11^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Flynn, 2016 ^12^ | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | HIGH | LOW | SOME CONCERNS | HIGH
Fulay, 2018 ^13^ | LOW | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Gonzalez-Nahm, 2019 ^14^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Grieger, 2014 ^15^ | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Hajianfar, 2018 ^16^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Hillesund, 2014 ^17^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Hillesund, 2018 ^18^ | LOW | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Hrolfsdottir, 2019 ^19^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Hwang, 2022 ^20^ | SOME CONCERNS | VERY HIGH | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH
Knudsen, 2008 ^21^ | HIGH | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Lecorguillé, 2020 ^22^ | SOME CONCERNS | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Li, 2021 ^23^ | HIGH | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Lipsky, 2023 ^24^ | HIGH | LOW | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Lu, 2016 ^25^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Makarem, 2022 ^26^ | SOME CONCERNS | LOW | LOW | HIGH | HIGH | LOW | HIGH | HIGH
Maldonado, 2022 ^27^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Miele, 2021 ^28^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Mikeš, 2022 ^29^ | SOME CONCERNS | VERY HIGH | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | VERY HIGH
Navarro, 2019 ^31^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Navarro, 2020 ^30^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Okubo, 2012 ^32^ | SOME CONCERNS | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Okubo, 2023 ^33^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Paknahad, 2019 ^34^ | HIGH | SOME CONCERNS | LOW | HIGH | HIGH | LOW | SOME CONCERNS | HIGH
Parisi, 2020 ^35^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | HIGH | HIGH
Poon, 2013 ^36^ | SOME CONCERNS | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Reyes-López, 2021 ^37^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | HIGH | HIGH
Rifas-Shiman, 2009 ^38^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Rodriguez-Bernal, 2010 ^39^ | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Santos, 2021 ^40^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Sun, 2023 ^41^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Teixeira, 2021 ^42^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Xu, 2023 ^43^ | SOME CONCERNS | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH
Yamashita, 2022 ^44^ | SOME CONCERNS | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Yee, 2020 ^45^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Yisahak, 2021 ^46^ | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zhang, 2023 ^47^ | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | LOW | HIGH | HIGH
Zhu, 2019 ^48^ | HIGH | LOW | LOW | SOME CONCERNS | LOW | LOW | HIGH | HIGH
Zulyniak, 2017 ^49^ | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable determined using the “Risk of Bias in Non-randomized tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E) (published online Mar 24); doi: 10.1016/j.envint.2024.108602 ) *Low risk of bias except for concerns about uncontrolled confounding.