# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for 2 systematic reviews assessing the relationship between dietary patterns consumed during pregnancy and birth weight and gestational age.^†^ The literature search (Appendix 4) yielded 1,594 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 1,075 titles, 198 abstracts, and 265 full-texts articles. Reasons for full-text exclusion are in Appendix 5. Eleven additional articles were identified from the existing review^‡^ and 1 additional article was identified from the manual search. The body of evidence included 60 articles.

† Abrams SA, Andres A, Byrd-Bredbenner C, . Dietary Patterns Consumed During Pregnancy and Gestational Age at Birth: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR26

‡ Raghavan R, Dreibelbis C, Kingshipp BJ, . Dietary Patterns before and during Pregnancy and Gestational Age- and Sex-Specific Birth Weight: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2019. 10.52570/NESR.PB242018.SR0104.

Figure 2 Literature search and screen flowchart

The literature searches in PubMed, Embase, Cochrane, CINAHL, and Scopus retrieved 2,918 records after removing duplicates. 1 additional article was found with manual search methods. 11 were included from an existing review. 1,075 titles, 198 abstracts, and 265 full-texts were excluded. 60 articles were included in the systematic review.

## Description of the evidence

This systematic review included 60 articles from 59 studies, including 50 articles from 50 prospective cohort studies (PCS; 3 articles analyzed multiple PCS),^1–50^ 10 articles from 8 randomized controlled trials (RCT),^51–60^ and 1 article from a non-randomized controlled trial (NRCT),^58^ that address the relationship between dietary patterns during pregnancy and birth weight (Table 8). The analytic sample sizes for the RCT and NRCT ranged from 196 to 1,095, with approximately half including ≥500 participants.^51–55,58,60^ For the PCS, the analytic sample sizes ranged from 94 to 72,317, but only 9 studies had <500 participants.^1,3,15,24,27,34,35,37,42^ The studies were conducted in: the United States (15 articles),^3,4,10,13,14,24,26,27,36,38,45,46,48,56,59^ Spain (7 articles),^5,9,39,52–54,58^ China (6 articles),^8,23,25,41,47,60^ Norway (4 articles),^11,17,18,57^ Brazil (4 articles),^1,28,40,42^ the United Kingdom (3 articles),^6,12,51^ Japan (3 articles),^32,33,44^ Ireland (3 articles),^6,30,31^ Australia (3 articles),^15,43,55^ Iran (2 articles),^16,34^ France (2 articles),^6,22^ Mexico (2 articles),^37,50^ Italy (2 articles),^2,35^ and Singapore,^7^ Poland,^6^ the Netherlands,^6^ Korea,^20^ Iceland,^19^ Greece,^5^ Denmark,^21^ Czechia,^29^ and Canada^49^ (1 article each).

### Population

#### Age

Participant age generally ranged from the mid-twenties to early-thirties in the PCS.^1–50^ The mean age of participants in the RCT or NRCT was slightly higher, ranging from 29 years to 37 years.^51–60^

#### Health status

##### Pre-pregnancy BMI

All but 2 articles^16,21^ reported information regarding pre-pregnancy BMI. Approximately 70% of articles enrolled participants with a mean BMI or a majority of participants with BMI <25.^1,2,4–11,13,17–20,22,23,25,26,28–33,35,38,39,41–44,47,49,52–55,57,58,60^ Among the remaining articles, 13 enrolled participants with a mean BMI or a majority of participants with BMI ≥25,^3,15,24,27,34,36,37,40,45,46,48,50,56^ while 4 enrolled participants with a mean BMI or a majority of participants with BMI ≥30.^12,14,51,59^

##### Diabetes and gestational diabetes

Eighteen articles did not provide information on diabetes, including gestational diabetes mellitus (GDM), in the current pregnancy.^2,3,6,9,14–16,19,21,29–33,39,41,46,50^ The percent of participants with GDM ranged from approximately 0% to 28% in the 26 articles that reported this information.^4,7,8,10,12,13,18,24,27,28,34–36,38,40,44,45,47–49,51–56^ Additionally, 14 articles reported that no participants had chronic or pre-pregnancy diabetes^7,12,13,17,18,24–26,34,36,40,55–57^ and 5 articles reported that approximately 1% to 7% of participants had chronic or pre-pregnancy diabetes.^5,10,27,45,54^ One final article reported that 32% of participants had either diabetes or GDM.^43^

##### Hypertensive disorders of pregnancy

Thirty articles did not provide information on current hypertensive disorders of pregnancy (HDP).^1–3,6,9,11,14–17,19,21–24,27,29–34,36,39,40,43,46,49,50,56,60^ Gestational hypertension ranged from approximately 0% to 5% of participants in the 7 articles that reported this information.^5,20,41,52–55^ Pre-eclampsia, which was reported in 11 articles, ranged from approximately 1.5% to 8.5% of participants.^4,7,8,12,18,28,37,38,44,47,51–55^ Additionally, 3 articles reported that none of the participants had chronic hypertension,^25,26,57^ while 1 article noted that approximately 2% of participants had chronic hypertension.^45^ Approximately 0% to 11% of participants in 7 articles had unspecified HDP,^7,13,35,37,44,47,48^ while an eighth article reported that approximately 23% of participants had unspecified HDP.^45^

#### Race and/or ethnicity

Twenty-five articles did not provide information on the race and/or ethnicity of participants.^1,2,5,11,16,17,19–22,29–34,37,41–44,47,60^ Across the remaining 35 articles, individuals of several races and/or ethnicities were represented, including participants who were White, Black or African American, Hispanic or Latino, Asian or Pacific Islander, and American Indian or Alaska Native.

##### White

White individuals made up approximately 15% to 100% of participants across 28 articles.^4,6,9,10,12–15,18,24,26,28,36,38,40,45,46,48,49,51–57,59^ Of these, 20 articles reported having a study sample consisting predominantly of White participants.^4,6,9,10,12–15,18,24,26,36,38,45,49,52–55,57,59^

##### Black or African American

Fifteen articles reported that approximately 2% to 35% of participants were Black or African American,^4,9,12,13,24,26,38,45,46,48,49,51,54,56,59^ with 1 additional article reporting that 70% of participants were Black.^14^

##### Hispanic or Latino

Thirteen articles reported that approximately 7% to 41% of participants were Hispanic or Latino,^4,9,13,24,26,27,45,46,48,52–54,56^ with 3 additional articles reporting that >75% of participants were Hispanic or Latino.^3,39,58^

##### Asian or Pacific Islander

Next, 12 articles reported that approximately 1% to 44% of participants were Asian or Pacific Islander,^9,12,13,24,26,45,46,48,49,51,54,55^ with 4 additional articles reporting that >95% of participants were Asian or Pacific Islander.^7,8,23,25^

##### Individuals of other races and/or ethnicities

Only 1 study specifically reported the inclusion of participants who were American Indian or Alaska Native (0.3%).^24^ Seventeen articles reported an “other” category with proportions ranging from 0.3% to 17%.^4,12–14,24,26,38,39,45,48,49,51–53,55,56,59^ One article reported that 57% of participants were non-White.^40^

#### Socioeconomic position

All but 3 articles^16,21,51^ reported information on measures of participant socioeconomic position (SEP). The most common metrics included education, income, and occupation or employment.

##### Education

Forty-nine articles reported on participant education.^1–14,17–20,22–33,36–50,52,53,56–58^ Of these, the majority of participants had at least some tertiary, college, or university education.^3,4,6–12,14,17–20,22–26,30–33,36–38,41–46,48,49,52,53,56,57^ However, in 11 articles most participants had a high school education (or equivalent) or less.^1,2,5,13,27–29,39,47,50,58^

##### Income, occupation or employment, and other measures

Twenty-six articles reported on participant income.^1,8,11,13,14,18,20,22–25,27,28,30–32,36,38,43–46,48,49,56,59^ While 4 articles had a majority of participants with less than a “middle” class income,^1,14,27,28^ 22 articles had a majority of participants with a “middle” class income or higher, or the level of income was unclear.^8,11,13,18,20,22–25,30–32,36,38,43–46,48,49,56,59^

Eighteen articles reported on participant occupation or employment.^2–4,18,22,24,28,32,34,35,37,39,43,46,53,58,60^ Eleven of these articles reported that the majority of participants were employed outside of the home.^2,4,18,22,28,35,39,43,46,53,60^ Ten articles used other measures to assess SEP among participants.^4,9,12,15,40,41,45,46,54,55^ The most common of these included assessments of socioeconomic index or level, with 5 articles reporting that the majority of participants had moderate or higher SEP^9,40,41,54,55^ and 2 articles reporting that the majority of participants had lower SEP.^12,15^ Three articles reported the type of health insurance utilized by participants; all noted that the majority of participants had private health insurance.^4,45,46^

#### Smoking

Thirteen articles did not provide information on smoking.^3,8,12,20,24,28,34,37,38,41,47,50,51^ Among the 40 articles that reported on smoking during pregnancy, 4 did not include any current smokers,^16,56,57,59^ 22 reported that <10% of participants smoked during pregnancy,^1,2,7,10,11,17–19,27,29,33,36,43,46,48,49,52–55,58,60^ and 14 reported that approximately 11% to 42% of participants smoked during pregnancy.^5,6,9,13–15,22,30–32,35,39,40,44^ Additionally, 1 article noted that 30% of participants were exposed to passive smoking during pregnancy.^25^ Smoking ever or before pregnancy was examined in several articles, with 11 reporting that approximately 4% to 37% of participants were former smokers^4,10,19,23,29,32,33,40,42,44,49^ and 3 reporting that approximately 23% to 44% of participants had ever smoked.^21,26,45^

### Interventions/exposures and comparators

#### Dietary pattern methodology

Dietary patterns were assessed primarily using an experimental diet, index/score analysis, and factor/cluster analysis, with few studies using reduced rank regression or other methods. Specifically, 10 articles from 8 RCT and 1 NRCT assigned participants to an experimental diet,^51–60^ 26 articles used at least 1 index or score to assess dietary patterns,^3,5,6,9,10,13,14,17–19,24,26,30,31,33,35–41,43,45,46,48,50^ 23 articles used factor or cluster analysis,^2–4,7,8,11,12,15,16,21,23,25,27–29,32,34,42,44,46,47,49,50^ and 4 articles used reduced rank.^1,20,22,44^ Additionally, 1 article assessed dietary patterns based on a partial least squares method.^44^ The dietary pattern components are detailed in Table 5 and visualized in Appendix 6.

Table 5 Dietary pattern components^*^ * Abbreviations: AHEI: Alternative Healthy Eating Index; d: day; DASH: Dietary Approaches to Stop Hypertension; DHA: docosahexaenoic acid; DP: dietary pattern(s); EPA: eicosapentaenoic acid; EVOO: extra virgin olive oil; FIGO: International Federation of Gynecology and Obstetrics; g: gram(s); HEI: Healthy Eating Index; kcal: kilocalorie(s); mg: milligram(s); MUFA: monounsaturated fatty acids; OMNI: Optimal Macronutrient Intake; PCA: principal component analysis; PLS: partial least squares; PUFA: polyunsaturated fatty acids; SFA: saturated fatty acids; SSB: sugar-sweetened beverages; svg: serving; T#: Trimester; ug: microgram(s); w/: with; wk: week

Reference | Dietary pattern | Dietary pattern components
Al Wattar, 2019^51^ | Mediterranean-style supplemented w/ mixed nuts and EVOO | Positive: Olive oil (as main fat and svg/d); Nuts (including peanuts) Vegetables; Fruit (including juice); Pulses; Fish or shellfish; White meat over red meat; Negative: Red or processed meat; Butter, margarine, or cream; SSB; Commercial sweets or pastries
Assaf-Balut, 2017^52^; Assaf- Balut, 2019^53^ | Mediterranean-style supplemented w/ pistachios and EVOO | Positive: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; Negative: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries
Crovetto, 2021^54^ | Mediterranean-style | Positive: EVOO; walnuts; vegetables; fresh fruit; dairy products; whole grains; sofrito; legumes; fish; fatty fish; white meat; Negative: Refined grains; red meat; processed meat; soda drinks; commercial bakery foods, sweets, and pastries; butter, margarine, or cream
Dodd, 2019^55^ | HEI | Positive: Vegetables; fruit; dairy
Gallagher, 2018^56^ | HEI-2010 | Positive: Vegetables; fruits; whole grains; total protein foods; plant proteins; seafood; dairy; fatty acids; Negative: Refined grains; energy from added sugars, solid fats, alcohol; sodium
Khoury, 2005^57^ | Cholesterol-lowering diet advice | Positive: Fish and fish products; fatty fish and fish products; rapeseed-based margarine; oils; olive oil; rapeseed oil; nuts, olives, and seeds; vegetables; fruits; Negative: Fatty milk; meat and meat products; fatty minced meat; butter; hard margarines
Melero, 2020^58^ | Mediterranean-style supplemented w/ pistachios and EVOO | Positive: Vegetables; dishes with tomato sauce (tomato, garlic, onion, leek, olive oil); pulses; nuts; fish; white meat over red meat; olive oil; olive oil as principal cooking fat.; Negative: Commercial pastries; red meat or sausages; animal fat; SSB; Alcohol and fruit (including juice) components excluded
Van Horn, 2018^59^ | DASH-style | Positive: Vegetables (not potatoes); nuts and legumes; fruit (including fruit juice); whole grains; low-fat dairy; Negative: Red and processed meat; sweetened beverages; sodium
Zhao, 2022^60^ | Mediterranean-style w/ recommended additional pistachios and EVOO | Positive: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; Negative: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries
Index/Score Analysis
Ancira-Moreno, 2020^50^ | Maternal Diet Quality Score | Positive components: fruits and vegetables (≥400/d), PUFA (≥6% of total energy), low fat dairy products (2 svg/d), legumes (2 svg/d); Negative components: red meat (≤500 g/wk), saturated fat and/or added sugars (<10% of energy)
Berube, 2023^3^ | HEI-2015 | Positive components: total fruits, whole fruits, total vegetables, greens and beans, whole grains, dairy, total protein, seafood and plant protein, fatty acids.; Negative components: refined grains, sodium, saturated fat, added sugars.
Chatzi, 2012^5^ | Mediterranean Diet | Positive components: vegetables, legumes, fruits and nuts, cereals, fish and seafood, dairy products, and the ratio of MUFA:SFA; Negative components: all types of meat
Chen, 2021^6^ | DASH | Positive components: fruits, vegetables excluding potatoes, total grains, non-full-fat dairy products, nuts/seeds/legumes.; Negative components: red and processed meats, SSB/sweets/added sugars, sodium.
Díaz-López, 2022^9^ | Relative Mediterranean Diet | Positive components: fruits, vegetables, legumes, cereals, fresh fish and olive oil; Negative components: meat, dairy, alcohol
Emond, 2018^10^ | AHEI-2010 | Positive components: fruits, vegetables, whole grains, nuts and legumes, long-chain omega-3 fatty acids (EPA+DHA), PUFA; Negative components: sugary beverages, red and processed meats, trans fatty acids, sodium.; Modified to exclude moderate alcohol component.
Fulay, 2018^13^ | DASH | Positive components: fruits; vegetables; whole grains; nuts/legumes; low-fat dairy; Negative components: sodium; SSB; red and/or processed meats
Fulay, 2018^13^ | DASH OMNI | Positive components: fruits; vegetables; whole grains; nuts/legumes; low-fat dairy; MUFA and PUFA; Negative components: sodium; SSB; red and/or processed meats
Gonzalez-Nahm, 2019^14^ | AHEI-2010 | Positive components: vegetables, fruit, whole grains, nuts and legumes, long-chain omega-3 fatty acids (DHA and EPA), PUFA; Negative components: SSBs, red/processed meat, trans fat, sodium Modified to exclude alcohol component
Hillesund, 2014^17^ | New Nordic Diet | Positive components: (i) eating ≥24 main meals/wk; (ii) eating Nordic fruits ≥5 times/wk; (iii) eating root vegetables ≥5 times/wk; (iv) eating cabbage ≥2 times/wk; (v) eating potatoes ≥one-third of total occasions of eating potatoes, rice or pasta; (vi) choosing whole grain bread more often than refined bread; (vii) eating oatmeal .monthly; (viii) eating fish/game/berries about 2 times/wk; (ix) drinking milk more often than juice; and (x) drinking .6 times as much water as SSB
Hillesund, 2018^18^ | Norwegian Fit For Delivery | Positive components: regular meals; drinking water when thirsty; vegetables w/ dinner; fruits and vegetables between meals; reading nutrition labels before buying; Negative components: sweets and snacks without appreciation; large portion sizes of unhealthy foods; added sugar; salt; eating beyond satiety
Hrolfsdottir, 2019^19^ | Dietary risk score | Negative components: Not eating a varied diet (excluded/avoided any of the main food groups: cereal, vegetables/fruits, fish, meat, eggs, high-fat foods, or dairy), fruits/vegetables <5/d, dairy <2/d, whole grain products <2/d, sugar/artificially sweetened beverages ≥5/d, dairy ≥5/d
Lipsky, 2023^24^ | HEI-2015 | Positive components: total fruit, whole fruit, total vegetables, greens and beans, whole grains, dairy, total protein, seafood and plant proteins, fatty acids.; Negative components: refined grains, sodium, added sugars, saturated fats.
Makarem, 2022^26^ | Alternative Mediterranean Diet | Positive components: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA:SFA; Negative component: Red and Processed Meat; Moderate component: Alcohol
Navarro, 2019^31^ | HEI-2015 | Positive components: total fruits, whole fruits, total vegetables, greens and beans, total protein containing foods, seafood and plant proteins, whole grains, dairy, ratio of PUFAs and MUFAs to SFAs; Negative components: refined grains, sodium, added sugars, saturated fats
Navarro, 2020^30^ | HEI-2015 | Positive components: total fruit, whole fruit, total vegetables, greens and beans, whole grains, dairy, total protein, seafood and plant proteins, fatty acids.; Negative components: refined grains, sodium, added sugars, saturated fats.
Okubo, 2023^33^ | Balanced diet score | Positive components: Grain dishes, vegetable dishes, fish and meat dishes, milk, fruits.; Negative components: snacks and alcoholic beverages, sodium from seasonings
Parisi, 2020^35^ | FIGO Recommendations | Positive components: meat, fruit and vegetables, fish, dairy products, whole cereals, hemoglobin concentration, folic acid supplementation, iodized salt, sun exposure.; Negative components: sweets and snacks.
Poon, 2013^36^ | AHEI Pregnancy | Positive components: vegetables, whole fruit, whole grains, nuts and legumes, long-chain omega-3 fats (EPA+DHA), PUFA, calcium, folate, iron.; Negative components: SSB, red/processed meat, trans fat, sodium.
Poon, 2013^36^ | Alternative Mediterranean Diet | Positive components: vegetables, legumes, fruits, nuts, whole grains, fish, MUFA:SFA; Negative component: red and processed meat
Reyes-López, 2021^37^ | AHEI-2010 Pregnancy | Positive components: vegetables, fruit, whole grains, nuts and legumes, fish, PUFA, calcium, iron, folate.; Negative components: SSBs and fruit juice, red/processed meat, trans fat.
Rifas-Shiman, 2009^38^ | AHEI Pregnancy | Positive components: vegetables, fruit, ratio of white to red meat, fiber, ratio of PUFA to SFA, and folate, calcium, and iron from foods; Negative component: trans fat
Rodríguez-Bernal, 2010^39^ | AHEI Pregnancy | Positive components: vegetables (5 svg/d), fruit (4 svg/d), nuts and soy (1 svg/d), ratio of white meat (fish and poultry) to red meat (≥4:1), cereal fiber (15g/d), ratio of polyunsaturated to saturated fat (≥1), and folate (≥600g/d), calcium (≥1000mg/d), and iron (≥27mg/d) from foods; Negative components: trans fat
Santos, 2021^40^ | Diet Quality Index Adapted for Pregnant Women | Positive components: (/1000 kcal): vegetables ≥1.5 svg; legumes ≥0.05 svg; fresh fruits ≥1.5 svg; fibers ≥28.0 g; omega-3 ≥1.4 g; calcium ≥800 mg; folate ≥520 ug; iron ≥22 mg; Negative components: ultra-processed foods ≥45% of kcal
Sun, 2023^41^ | Dietary diversity score | Positive components: starchy staples, beans and peas, nuts and seeds, dairy, flesh foods (meat, fish), eggs, vitamin A-rich dark green vegetables, other vitamin A-rich fruits and vegetables, other vegetables, other fruits
Xu, 2023^43^ | Dietary behaviour score | Positive components: fruit, vegetables.; Negative components: processed meat, fast food, chips, soft drink
Xu, 2023^43^ | Junk food score | Positive components: processed meat, fast food, chips, soft drink
Yee, 2020^45^ | HEI-2010 | Positive components: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids; Negative components: Refined Grains; Empty Calories (i.e., energy from solid fats, alcohol, and added sugars); Sodium
Yisahak, 2021^46^ | AHEI-2010 | Positive components: vegetables, fruits, whole grains, nuts and legumes, long-chain omega-3 fatty acids (EPA and DHA), PUFAs.; Negative components: SSB red/processed meats, trans fat, sodium. Modified to eliminate alcohol component.
Yisahak, 2021^46^ | Alternative Mediterranean Diet | Positive components: vegetables excluding potatoes, legumes, fruit, nuts, whole grains, fish, ratio of MUFA:SFA.; Negative components: red and processed meats.; Modified to eliminate alcohol component.
Yisahak, 2021^46^ | DASH | Positive components: vegetables, fruits, whole grains, low-fat dairy, nuts, seeds, legumes.; Negative components: red and processed meat, SSB, sodium.
Zhu, 2019^48^ | HEI-2010 | Positive components: total fruit, whole fruit, total vegetables, greens and beans, whole grains, dairy, total protein foods, seafood and plant proteins, fatty acids.; Negative components: refined grains, sodium, empty calories from solid fats and added sugars.; Alcohol component excluded from empty calories
Factor/Cluster Analysis
Ancira-Moreno, 2020^50^ | Healthier DP | Higher intake of white meat and eggs, low fat dairy products, cereals and tubers, fruits and vegetables.; Lower intake of high saturated fat and/or added sugar foods, SSB, legumes.
Ancira-Moreno, 2020^50^ | Mixed DP | Higher intake of SSB, red and processed meat, cereals and tubers, supplements.; Lower intake of oils and fats, high saturated fat and/or added sugar foods, white meat and eggs, low fat dairy products.
Barchitta, 2023^2^ | Cluster 1 (reference group) | Higher intake of potatoes, cooked and raw vegetables, legumes, fruits, nuts, yogurt, rice, wholemeal bread, white meat, offal, fish, eggs, butter and margarine, coffee, tea, soup.
Barchitta, 2023^2^ | Cluster 2 | Higher intake of milk, pasta, white bread, shellfish, vegetable and olive oils, sweets, fruit juices, dipping sauces, salty snacks, fries.
Berube, 2023^3^ | Western | Higher intake of cakes, pies, and cookies, processed meats, American dishes, candy, sweetened beverages, salty snacks.
Berube, 2023^3^ | Fruits and vegetables | Higher intake of nonstarchy vegetables, starchy vegetables, beans and peas, meat/vegetable soups, whole fresh fruit.
Bodnar, 2024^4^ | High fruits, vegetables, whole grains, and plant proteins | Higher intake of vegetable medley/other vegetables, apples/pears, tomatoes, lettuce, broccoli, bananas, spinach/greens, strawberries/ other berries, avocado, citrus fruits, tofu/meat substitutes, peaches/plums/apricots/nectarines, yogurt, salad dressing, peas/string beans, nuts/ seeds/nut or seed mixed dishes, sweet potatoes, other fruit/fruit salad, melon, coffee.
Bodnar, 2024^4^ | Sandwiches and snacks | Higher intake of coffee, alcoholic beverages, whole wheat bread, cold cuts, skim milk, diet soda/diet fruit drinks, pretzels/fat-free crackers/rice cakes, nuts/seeds/nut or seed mixed dishes, condiments, salad dressing, cream, unfried chicken or turkey/ mixed dishes, crackers, reduced fat cheese, jam/ jelly, white breads, sugars/honey, regular cheese, mayonnaise, nondairy creamer/cream substitutes.
Bodnar, 2024^4^ | Beverages, refined grains, and mixed dishes | Higher intake of reduced fat milk, 100% juice (not orange or grapefruit), rice/rice mixed dishes, 100% orange or grapefruit juice, Mexican mixed dishes, dried beans, soup, liver/other organ meats, whole milk, cold cereals, hot cereal, oils, vegetable juice, other white potatoes, vegetable mixed dishes, other meat/other meat mixed dishes, syrups/ toppings, eggs/egg mixed dishes, pancakes/ waffles/French toast/Pop Tarts, coleslaw.
Bodnar, 2024^4^ | High fat, sugar, and sodium | Higher intake of regular soda, fried chicken or fried turkey, fried white potatoes, burgers, sausage/ franks/bacon/ribs, fruit drinks, chips/popcorn/other salty snacks, candy, pizza, grain desserts, other meat/other meat mixed dishes, white yeast breads, pancakes/waffles/French toast/Pop Tarts, dairy desserts, margarine, quick breads, beef/beef mixed dishes, crackers, other white potatoes, mayonnaise.
Chia, 2016^7^ | Vegetable, fruit, and white rice | Higher intakes of vegetables, fruits, plain white rice, whole-grain bread, fish, and nuts and seeds.; Lower intakes of fried potatoes, burgers, carbonated and sweetened drinks, and flavored rice.
Chia, 2016^7^ | Seafood and noodle | Higher intakes of soup, seafood, fish and seafood products, noodles (flavored and in soup), and low-fat red meat.; Lower intakes of legumes, ethnic bread, white rice, and curry-based gravies.
Chia, 2016^7^ | Pasta, cheese, and processed meat | Higher intake of pasta-, tomato-, and cream-based gravies, cheese, and processed meat.
de Seymour, 2022^8^ | Fish, poultry and vegetables | Higher in fish; poultry; legumes and bean products; green leafy vegetables; root vegetables; other vegetables; seafood; fruits; eggs; organ meats; beverages; bread; dairy; soup; nuts.
de Seymour, 2022^8^ | Pasta, sweetened beverages, oils and condiments | Higher in pasta; sweetened beverages; oils and condiments; fast food.
Englund-Ogge, 2019^11^ | High prudent | Higher intake of raw and cooked vegetables, salad, onion/leek/garlic, fruit and berries, nuts, vegetable oils, water as beverage, whole grain cereals, poultry, and fibre rich bread.; Lower intake of processed meat products, white bread, pizza/tacos.; Individuals in high prudent were in highest tertile of high prudent and in lowest or middle tertile of high western and high traditional.
Englund-Ogge, 2019^11^ | High western (reference group) | Higher intake of salty snacks, chocolate and sweets, cakes, French fries, white bread, ketchup, sugar sweetened drinks, processed meat products, pasta.; Lower intake of lean fish, fibre rich bread.; Individuals in high western were in highest tertile of high western and in lowest or middle tertile of high prudent and high traditional.
Englund-Ogge, 2019^11^ | High traditional | Higher intake of boiled potatoes, fish products, gravy, lean fish, margarine, rice pudding, low fat milk, cooked vegetables.; Lower intake of poultry, pizza/tacos.; Individuals in high traditional were in highest tertile of high traditional and in lowest or middle tertile of high prudent and high western.
Flynn, 2016^12^ | Fruit and vegetable | Higher intake of bananas, citrus fruit, dried fruit, fresh fruit, green vegetables, pulses, root vegetables, salad vegetables, tropical fruit, yoghurt.
Flynn, 2016^12^ | African/Caribbean | Higher intake of red meat, cassava, white meat, pilau/fried/jollof rice, plantain, white/brown/basmati rice, fish.
Flynn, 2016^12^ | Processed | Higher intake of chocolate, crisps, green vegetables, potatoes, processed/meat products, root vegetables, squash/fizzy drinks, sugar free drinks, takeaway/oven chips.
Flynn, 2016^12^ | Snacks | Higher intake of biscuits/cookies, cakes/pastries, chocolate, full fat cheese, sweets.
Grieger, 2014^15^ | High-protein/fruit | Higher intake of fish, meat, chicken, fruit, whole grains.
Grieger, 2014^15^ | High-fat/sugar/takeaway | Higher intake of takeaway foods, potato chips, refined grains, added sugar.
Grieger, 2014^15^ | Vegetarian-type | Higher intake of vegetables, whole grains, legumes.
Hajianfar, 2018^16^ | Healthy | Higher intake of green vegetables, leafy vegetables, colored vegetables, fruit, dairy low fat, poultry, bulky vegetables, red meat, citrus, nuts, fish, olive, marinades, sweat fruit, egg, unsaturated fat.
Hajianfar, 2018^16^ | Western | Higher intake of fruit, citrus, nuts, fish, fruit juice, sweets and dessert, sugar, saturated fat, sweet fruit, potato, legumes, coffee, egg, pizza, high fat dairy, soft drink, whole grain, processed meat. Lower intake of refined grain.
Hajianfar, 2018^16^ | Traditional | Higher intake of colored vegetables, olive, sugar, salt, spices, unsaturated fat, garlic onion, tea, refined grain.
Knudsen, 2008^21^ | Western (reference group) | Highest intake of high-fat dairy, refined grains, processed and red meat, animal fat (butter and lard), potatoes, sweets, beer, coffee, and high-energy drinks.; Lowest intake of fruits and vegetables (35% of energy intake from fat)
Knudsen, 2008^21^ | Health conscious | Higher intakes of fruits, vegetables, fish, poultry, breakfast cereals, vegetable juice, and water.; Lowest intakes of meat and fat of animal origin (25% of energy intake from fat).
Knudsen, 2008^21^ | Intermediate | Higher intakes of low-fat dairy and fruit juice; consumption of the remaining food groups in between Western and Health conscious DPs (30% of energy intake from fat).
Li, 2021^23^ | Beans-vegetables | Higher intake of root vegetables, mushrooms and algae, melon and solanaceous vegetables, beans and bean products (i.e., soybean, mung bean, soybean milk, bean curd, and so on), leafy and cruciferous vegetables.
Li, 2021^23^ | Fish-meat-eggs | Higher intake of red meat, freshwater fishes, eggs.
Li, 2021^23^ | Nuts-whole grains | Higher intake of nuts, whole grains, dairy products (i.e., milk, milk powder, and yogurt).
Li, 2021^23^ | Organ-poultry-seafood | Higher intake of animal organ and blood, seafood, poultry.
Li, 2021^23^ | Rice-wheat-fruits | Higher intake of rice and wheat products, fruits.
Lu, 2016^25^ | Varied | Higher intakes of mixed foods, including noodles, bread, root vegetables, melon vegetables, mushrooms, sea vegetables, bean vegetables, processed vegetables, poultry, animal organ meat, fish, other seafood, bean products, yoghurt, sweet beverages, puffed food, confectioneries, and snacks.
Lu, 2016^25^ | Dairy | Higher intakes of milk products (including fresh milk, pasteurized milk, milk powder, and formula for pregnant women) and lower intakes of whole vegetables.
Lu, 2016^25^ | Meats | Higher intakes of red and processed meat.
Lu, 2016^25^ | Fruits, nuts, and Cantonese desserts | Higher intakes of fruits, nuts, and Cantonese desserts.
Lu, 2016^25^ | Vegetables | Higher intakes of leafy and cruciferous vegetables.
Lu, 2016^25^ | Cereals, eggs, and Cantonese soups (reference group) | Higher intakes of rice, pasta, porridge, eggs, and Cantonese soups.
Maldonado, 2022^27^ | Solid fat, refined grain, and cheese | Higher intake of milk, cheese, fruit juices, tomatoes, other vegetables, white potatoes, legumes, seafood, refined grains, meat, processed meats, poultry, eggs, soy protein, nuts and seeds, oils, solid fats, added sugar.; Lower intake of yogurt, citrus, melons, berries, other fruits, dark green vegetables, other red and orange vegetables, other starchy vegetables, whole grains.
Maldonado, 2022^27^ | Vegetables, oils, and fruit | Higher intake of milk, yogurt, cheese, citrus, melons, berries, other fruits, fruit juices, dark green vegetables, tomatoes, other red and orange vegetables, other vegetables, white potatoes, other starchy vegetables, legumes, seafood, whole grains, meat, processed meats, poultry, eggs, soy protein, nuts and seeds, oils, added sugar.; Lower intake of refined grains, solid fats.
Miele, 2021^28^ | Obesogenic | Higher in ultra-processed and processed foods using NOVA classification (refined carbohydrate; fats; sweets).
Miele, 2021^28^ | Intermediate | Lower consumption of same food groups as “Obesogenic DP”.
Miele, 2021^28^ | Vegetarian | Higher in dairy; fruits; vegetables.
Miele, 2021^28^ | Protein | Higher in fatty meats; eggs; beans; very low quantity of natural foods (using NOVA classification).
Miele, 2021^28^ | Traditional (reference group) | Higher in beans; meats; eggs; natural or minimally processed foods (using NOVA classification).
Mikeš, 2022^29^ | Unhealthy | Higher intake of fried potatoes, offal, fish and fish products, pizza, doughnuts and omelettes, fried food, poultry, cake and pies, processed meat, pasta, cola drinks, wafers, chocolates and sweets, red meat, sweet drinks.
Mikeš, 2022^29^ | Healthy/traditional | Higher intake of root vegetables, cheese, milk, dairy products, fresh fruits, leafy vegetables, salads, wholemeal bread, boiled potatoes, juice, herbal tea, honey, white bread.
Okubo, 2012^32^ | Meat and eggs | Higher intakes of beef & pork, processed meat, chicken, eggs, butter, & dairy products.
Okubo, 2012^32^ | Wheat products | Higher intakes of bread, confectioneries, fruit & vegetable juice, & soft drinks.
Okubo, 2012^32^ | Rice, fish, and vegetables (reference group) | Higher intakes of rice, potatoes, nuts, pulses, fruits, green & yellow vegetables, white vegetables, mushrooms, seaweeds, Japanese & Chinese tea, fish, shellfish, sea products, miso soup & salt-containing seasoning.
Paknahad, 2019^34^ | High carbohydrate-lower fat | High intake of potato; fried potato; flour; egg; cooked carrots; pickles; noodle soup; beans; pomegranate; corn and maize; lentils; low-fat milk; lettuce; and raw carrot
Paknahad, 2019^34^ | High carbohydrate-higher fat | High intake of pea; soybean; fish; cabbage; cooked spinach; vegetable; high-fat milk; butter; tomato; cucumber; soup; cooked beans; and diluted yogurt.
Paknahad, 2019^34^ | High fiber (reference group) | High intake of cantaloupe; melon; peach; nectarine; green tomatoes; plums; watermelons; pears; apricots.
Teixeira, 2021^42^ | Lentils, whole grains, and soups | Higher intake of lentils, wheat bread and brown rice, soups, popcorn, cereal ready to eat and oats, white cheese, desserts with fruits and jelly, simple cakes, soya beverages, beef jerky, nuts, crackers, soya sauce, tea (sweetened), beef, stuffed pasta, feijoada, fruits, yogurt (whole milk).; Lower intake of French bread and white rice.
Teixeira, 2021^42^ | Snacks, sandwiches, sweets and soft drinks | Higher intake of processed meats, sandwiches and snacks, sandwich sauces, desserts and sweets, soft drinks, pasta with meat sauce, stuffed pasta, yogurt with flavor, pork and frankfurters, bakery with filling, fried beef and fried chicken, fried egg or omelette, potato salad, with vegetables and mayonnaise, alcoholic beverages, chocolate milk, feijoada, potato or cassava, mozzarella cheese.; Lower intake of yogurt.
Teixeira, 2021^42^ | Seasoned vegetables and lean meats | Higher intake of potato salad, with vegetables and mayonnaise, vegetables, oil (for salad dressing), salt, lean meats and fish, potato or cassava, fruits, French bread and white rice, and unsweetened juices (natural or artificial).
Teixeira, 2021^42^ | Sweetened juices, bread and butter, rice and beans | Higher intake of sweetened juices (natural or artificial), butter or margarine, French bread and white rice, beans, whole milk, yogurt, fried egg or omelette, potato or cassava (fried).; Lower intake of unsweetened juices (natural or artificial), alcoholic beverages.
Yamashita, 2022^44^ | PCA1 – pre- to early-pregnancy | Higher intake of pulses, vegetables, fruits, mushroom, fish and shellfish.; Lower intake of milk and dairy products.
Yamashita, 2022^44^ | PCA1 – early- to mid-pregnancy | Higher intake of pulses, vegetables, fruits, mushroom, fish and shellfish.; Lower intake of milk and dairy products, alcohol beverage.
Yamashita, 2022^44^ | PCA2 – pre- to early-pregnancy | Higher intake of vegetables, eggs, milk and dairy products.; Lower intake of cereals, meat.
Yamashita, 2022^44^ | PCA2 – early- to mid-pregnancy | Higher intake of pulses, vegetables, eggs, milk and dairy products.; Lower intake of cereals, meat.
Yisahak, 2021^46^ | PCA pattern 1 | Higher intake of solid fat, nonwhole grains, white potatoes, meat (from beef, pork, veal, lamb, and game), cheese.
Yisahak, 2021^46^ | PCA pattern 2 | Higher intake of other vegetables (not potatoes, starchy, orange, or dark-green vegetables), dark-green vegetables, orange vegetables, seafood high in omega-3 fatty acids, seafood low in omega-3 fatty acids.
Zhang, 2023^47^ | Cereals-vegetables-fruits | Higher intake of cereals, tubers and their products, dark vegetables, light vegetables, fruits.
Zhang, 2023^47^ | Vegetables-poultry-aquatic products | Higher intake of dark vegetables, light vegetables, mushroom and algae, poultry, meat products, fish, shrimp, and other aquatic products.
Zhang, 2023^47^ | Milk-meat-eggs | Higher intake of milk, red meat (pork), meat products, eggs.
Zhang, 2023^47^ | Nuts-aquatic products-snacks | Fish, shrimp, and other aquatic products, eggs, bread, biscuits, chocolate, and other snacks, nuts.
Zulyniak, 2017^49^ | Plant-based | Higher intake of low fat dairy, fermented dairy, legumes, fresh seasonings, vegetable medley, other vegetables, whole grains, non-meat dishes, tea.; Lower intake of meat.
Reduced Rank Regression Analysis
Alves-Santos, 2019^1^ | Fast food and candies | High intakes of fast food and snacks; cakes, cookies, or crackers; and candies or desserts.; Low intakes of rice, beans, vegetables spices, and green vegetables or legumes.
Alves-Santos, 2019^1^ | Vegetables and dairy | High intakes of green vegetables or legumes, dairy products, fish, tea, fruits or fruit juices, and candies or desserts.; Low intakes of bread, sweetened and diet soda, and table sugar.
Alves-Santos, 2019^1^ | Beans, bread, and fat | High intakes of beans; cakes, or cookies, or crackers; bread and fats used as spreads.; Low intakes of fish, fruit or fruit juices, and noodles, pasta, roots, or tubers.
Hwang, 2022^20^ | DP 1 | Higher intakes of grains, green/yellow and light-colored vegetables, kimchi, legumes, fruits, meat, eggs, fish, seaweeds, tofu/soymilk, yogurt, nuts.
Hwang, 2022^20^ | DP 2 | Higher intakes of green/yellow and light-colored vegetables, kimchi, seaweed.; Lower intakes of white rice, poultry, meat, red meat by-products.
Hwang, 2022^20^ | DP 3 | Higher intakes of grains, milk, yogurt.; Lower intakes of rice cake, legumes, snacks, bony fish, tofu/soy milk.
Lecorguillé, 2020^22^ | Varied and balanced | Higher intake of low-fat milk, other vegetables, fish, meat, chicory, leek, cabbage, eggs and egg dishes, cereals, broccoli, liver.; Lower intake of snacks and confectionary, SSB.
Lecorguillé, 2020^22^ | Vegetarian tendency | Higher intake of other vegetables, chicory, cereals, fruits, bread. Lower intake of meat, liver.
Lecorguillé, 2020^22^ | Bread and starchy food | Higher intake of bread, rice, pasta, and others, sandwich. Lower intake of low-fat milk, fruits, fruit juice, SSB.
Yamashita, 2022^44^ | RRR – pre- to early-pregnancy | Higher intake of cereals, fruits.; Lower intake of alcohol beverage, non-alcohol beverage.
Yamashita, 2022^44^ | RRR – early- to mid-pregnancy | Higher intake of cereals, fruits, milk and dairy products.; Lower intake of alcohol beverage, non-alcohol beverage.
Other Method
Yamashita, 2022^44^ | PLS – pre- to earlypregnancy | Higher intake of cereals, fruits.; Lower intake of alcohol beverage, non-alcohol beverage.
Yamashita, 2022^44^ | PLS – early- to midpregnancy | Higher intake of cereals, fruits, mushroom, milk and dairy products.; Lower intake of alcohol beverage, non-alcohol beverage.

#### Timing of intervention or exposure assessment

Among the PCS, 13 articles assessed diet during the first trimester of pregnancy,^1,2,4,13,26,34,35,39,42,45–48^ 19 articles assessed diet during the second trimester of pregnancy,^5,8,10–12,15,17–23,25,28,30–32,49^ and 6 articles assessed diet during the third trimester of pregnancy.^3,7,27,29,36,43^ An additional 4 articles assessed diet a single time but the timing of the assessment occurred across multiple trimesters among participants,^14,16,40,41^ while 8 articles conducted multiple dietary assessments throughout pregnancy.^6,9,24,33,37,38,44,50^ Among trials, baseline occurred during the first trimester of pregnancy in 4 articles,^52,53,58,60^ during the second trimester in 5 articles,^51,54,56,57,59^ and in either the first or second trimester in 1 article.^55^

### Outcomes

#### Small-for-gestational age

Forty-nine articles reported SGA as an outcome.^2–15,17,18,20–23,25–29,32,35–42,44–46,48,49,51–60^ Most studies defined SGA based on birth weight ≤10th percentile,^3–15,17,18,20,22,23,25,27–29,32,35,36,38,40–42,44–46,48,49,51–60^ although 4 articles examined more stringent cut-offs, including below the fifth,^26^ the third,^51,54^ and the 2.5^th^ percentile.^21,26,51,54^ Additionally, 1 article defined SGA based on birth weight below negative 2 standard deviations based on ultrasound-derived curves,^11^ 1 article defined SGA based on birth weight less than the 80% confidence interval lower limit for customized models of predicted birth weight,^39^ and 2 articles did not describe how SGA was defined.^2,37^

#### Large-for-gestational age

Thirty-four articles reported LGA as an outcome.^1–3,7,8,10–14,17,18,22–25,27,35,36,38,40,46–49,51–56,58–60^ Nearly all studies defined LGA based on birth weight ≥90th percentile,^1,3,7,8,10–14,17,18,22–25,27,35,36,38,40,46–49,51–56,58–60^ although 1 article additionally used birth weight greater than 2 standard deviations based on ultrasound-derived curves to define LGA^11^ and 1 article did not define LGA.^2^

#### Low birth weight

Sixteen articles reported LBW as an outcome.^10,14–16,18,30,31,33,34,37,40,43,45,46,50,55^ All studies defined LBW based on a birth weight cut-off of 2,500 g.

#### Macrosomia

Fifteen articles reported macrosomia as an outcome.^8,10,12,14,18,19,30,31,34,40,43,45–47,55^ Fourteen articles defined macrosomia as birth weight greater than 4,000 g,^8,10,12,14,18,30,31,34,40,43,45–47,55^ while 2 articles defined macrosomia as birth weight greater than 4,500 g.^18,19^

## Synthesis of the evidence

### Small-for-gestational age

Twenty-six dietary patterns reported in 21 articles from 18 unique trials or cohorts significantly affected or were significantly associated with lower risk of SGA. Although the foods and food groups varied between dietary patterns, they were commonly characterized by higher intakes of vegetables, fruits, legumes, nuts and seeds, grains, fish/seafood, dairy, and unsaturated fats, as well as lower intakes of red and processed meat, added sugars, and saturated fats. Five dietary patterns reported in 4 articles from 7 unique cohorts were significantly associated with higher risk of SGA. The foods and food groups included were variable, but these dietary patterns were most commonly characterized by higher intakes of vegetables, grains, dairy, and added sugars. Seventy-nine dietary patterns reported in 38 articles from 42 unique trials or cohorts did not significantly affect or were not significantly associated with risk of SGA. A summary of the findings is included below, with detailed information presented in Table 8.

#### Intervention studies

Ten articles from 8 RCT^51–60^ and 1 article from 1 NRCT^58^ examined the relationship between dietary patterns consumed during pregnancy and risk of SGA.

Of these, 4 trials detected a significant effect of dietary patterns on lower risk of SGA, either overall or in a sub-group of the full sample^51–54,58,60^; no trials detected a statistically significant effect of dietary patterns on higher risk of SGA. Across these trials, the tested dietary patterns most commonly emphasized relatively higher consumption of vegetables, fruit, legumes, white meat, fish and seafood, nuts, and unsaturated fats and limiting consumption of red and processed meats, sugar sweetened beverages (SSB), and saturated fats.

First, in the Spanish St. Carlos GDM Prevention Study, participants were randomized to a Mediterranean-style diet with or without study provided extra virgin olive oil (EVOO) and pistachios; the risk of SGA was lower among those consuming EVOO and pistachios, an effect seen in the full sample^52,58^ and in a sample restricted to normoglycemic participants.^53^ A non-randomized comparison group received the same advice to consume a Mediterranean-style diet with EVOO and pistachios, but were not provided with these foods by the study; this group had a lower percent of infants born SGA than the control group, but these differences were small and statistically non-significant.^58^ A second RCT from Spain (IMPACT BCN) found that individuals randomized to a Mediterranean-style diet, along with provision of EVOO and walnuts, had lower odds of SGA and severe SGA (below the third percentile) compared to individuals receiving usual care.^54^ Another RCT, conducted in China, randomized participants to a Mediterranean-style diet, either with recommendation to consume EVOO and pistachios or with recommendation to restrict dietary fat, finding that participants randomized to consume a dietary pattern with EVOO and pistachios had a reduced risk of SGA.^60^ Finally, in the U.K.-based ESTEEM RCT, participants randomized to a Mediterranean-style diet with study-provided mixed nuts and EVOO had lower odds of SGA compared to participants randomized to usual care and antenatal dietary advice, but only among participants without chronic hypertension.^51^ Analysis of the overall sample, in addition to other sub-groups (BMI ≥30, normal triglyceride level) trended in the same direction but the confidence intervals included both higher and lower odds of SGA.^51^

The remaining trials did not detect a significant, overall or sub-group effect of dietary patterns consumed during pregnancy and risk of SGA.^55–57,59^ These trials included: the OPTIMISE RCT conducted in Australia;^55^ the U.S.-based LIFT RCT^56^; the CARRDIP RCT conducted in Norway^57^; and the U.S.-based MOMFIT RCT.^59^ The studies predominantly trended towards lower risk of SGA, with none trending towards higher risk of SGA, with randomization to dietary patterns that most commonly emphasized higher consumption of vegetables, fruit, legumes, fish and seafood, dairy, nuts and seeds, and unsaturated fats and lower consumption of red and processed meat, SSB, and saturated fats.

#### Observational studies

Thirty-nine articles that included data from 42 PCS examined the relationship between dietary patterns consumed during pregnancy and risk of SGA.^2–15,17,18,20–23,25–29,32,35–42,44–46,48,49^

Of these, 14 articles from 12 PCS detected a significant association between alignment with a dietary pattern and lower risk of SGA.^4–6,9,10,17,20–22,27,37,39,41,44^ Indices and scores among these studies included: Alternative Healthy Eating Index^10,37,39^; Dietary Approaches to Stop Hypertension^6^; Mediterranean-style diets^5,9^; New Nordic Diet^17^; and a dietary diversity score based on Food and Agriculture Organization guidelines.^41^ These indices and scores all or predominantly emphasized consumption of vegetables, fruits, grains, legumes, fish and seafood, dairy, nuts and seeds, and unsaturated fats, and limiting consumption of red and processed meat, added sugars, and saturated fats. Dietary patterns derived by factor or cluster analysis,^4,21,27^ reduced rank regression,^20,22,44^ or other methods^44^ tended to include several positive components consistent with those highlighted across the indices and scores, including vegetables, fruits, grains, and dairy. A range of other foods and beverages were emphasized across these dietary patterns but were less common or were more variable.

Few articles (4, which included data from 7 PCS) detected a significant association between alignment with a dietary pattern and higher risk of SGA.^11,32,42,49^ These dietary patterns were developed via factor/cluster analysis, and included a range of dietary patterns: “high prudent” and “high traditional” (compared to “western”),^11^ “wheat products”,^32^ “snacks, sandwiches, sweets, and soft drinks”,^42^ and “plant-based”.^49^ The components in these dietary patterns varied, but the most common positive components included vegetables, grains, dairy, and added sugars.

Twenty-one articles which included data from 24 PCS reported that 1 or more dietary patterns were not significantly associated with risk of SGA.^2–4,7,8,11,12,15,20,22,23,25,28,29,32,35,40,42,44,46,49^ Among studies utilizing indices and scores, although results were statistically null, most trended in the direction of lower SGA risk^3,6,13,36,38,41,45,46^ or the results were more neutral or unclear^5,6,14,26,35,38,40^; few trended clearly in the direction of higher SGA risk.^5,18,48^ The indices and scores generally emphasized similar components, with most including vegetables, fruits, grains (or whole grains specifically), legumes, dairy (or non-full-fat dairy specifically), nuts and seeds, and unsaturated fats as positive components, and red and processed meats, added sugars, saturated fats, and sodium as negative components. A larger proportion of the dietary patterns with non-significant associations were determined via a posteriori methods including factor/cluster analysis^2–4,7,8,11,12,15,23,25,28,29,32,42,44,46,49^ and reduced rank regression.^20,22^ These dietary patterns were more varied in their composition than those assessed with indices and scores. Similarly, non-significant trends for the risk of SGA were mixed and did not show a clear pattern among these dietary patterns, with some trending towards lower risk of SGA,^2–4,8,12,15,20,25,28,42,44,46,49^ others trending toward higher risk of SGA,^7,8,11,12,15,28,29,32,42,46^ and others still with more neutral or unclear trends.^11,12,22,29,44^

### Large-for-gestational age

Nine dietary patterns reported in 8 articles from 9 unique trials or cohorts significantly affected or were significantly associated with lower risk of LGA. Although the foods and food groups varied between dietary patterns, they were commonly characterized by higher intakes of vegetables, fruits, legumes, nuts and seeds, grains, and unsaturated fats, as well as lower intakes of red and processed meat and added sugars. Ten dietary patterns reported in 10 articles from 9 unique cohorts were significantly associated with higher risk of LGA. The foods and food groups included were variable, but these dietary patterns were most commonly characterized by higher intakes of vegetables, grains, and fish and seafood. Fifty-five dietary patterns reported in 28 articles from 30 unique trials or cohorts did not significantly affect or were not significantly associated with risk of LGA. A summary of the findings is included below, with detailed information presented in Table 8.

#### Intervention studies

Nine articles from 7 RCT^51–56,58–60^ and 1 article from 1 NRCT^58^ examined the relationship between dietary patterns consumed during pregnancy and risk of LGA. The trials all or predominantly emphasized consumption of vegetables, fruits, legumes, white meat, fish and seafood, nuts, and unsaturated fats, and limiting consumption of red and processed meat, SSB, and saturated fats.

Of these, only 1 trial detected a statistically significant effect of dietary patterns on risk of LGA.^52,53,58^ Specifically, in the previously described Spanish St. Carlos GDM Prevention Study, the risk of LGA was lower among those recommended a Mediterranean-style diet and provided EVOO and pistachios compared to those just receiving the dietary advice, an effect seen in the full sample^52,58^ and in a sample restricted to normoglycemic participants.^53^ The non-randomized comparison group, which received advice to consume a Mediterranean-style diet with EVOO and pistachios, had a lower percent of infants born LGA than the control group, but these differences were small and statistically non-significant.^58^

The remaining trials did not detect a significant, overall effect of dietary patterns consumed during pregnancy and risk of LGA.^51,54–56,59^ Further, the directionality of the trends was not consistent across these studies. While some trials tended toward reduced risk of LGA with the intervention diet (Chinese RCT,^60^ MOMFIT,^59^ OPTIMISE),^55^ others tended towards increased risk of LGA with the intervention diet (ESTEEM,^51^ LIFT),^56^ and 1 trial reported effectively no difference in LGA between groups (IMPACT BCN).^54^

#### Observational studies

Twenty-five articles that included data from 26 PCS examined the relationship between dietary patterns consumed during pregnancy and risk of LGA.^1–3,7,8,10–14,17,18,22–25,27,35,36,38,40,46–49^

Of these, 5 articles that included data from 8 PCS detected a significant association between alignment with a dietary pattern and lower risk of LGA.^11,13,24,40,49^ Three articles used indices and scores, examining alignment with a Dietary Approaches to Stop Hypertension-style diet,^13^ the Healthy Eating Index (HEI) 2015,^24^ and the Diet Quality Index Adapted for Pregnant Women,^40^ while the other 2 articles analyzed dietary patterns identified via factor/cluster analysis including a “high prudent”^11^ and a “plant-based” dietary pattern.^49^ These dietary patterns, regardless of methodology, predominantly emphasized similar foods and beverages including vegetables, fruits, whole grains, legumes, and nuts as positive components and red and processed meats as a negative component.

In contrast, 10 articles from 9 PCS detected a significant association between alignment with a dietary pattern and higher risk of LGA.^1,2,7,8,11,17,22,23,47,48^ Two articles used indices and scores, examining alignment with the New Nordic Diet^17^ and the HEI-2010,^48^ which both emphasize several similar food and beverage groups including vegetables, fruits, whole grains, and dairy as positive components, and refined grains and added sugars as negative components. The remaining 8 articles used factor/cluster analysis^2,7,8,11,23,47^ or reduced rank regression^1,22^ to identify a range of dietary patterns, including: “varied and balanced,”^22^ “fast food and candies,”^1^ “cereals, vegetables, fruits,”^47^ “fish, meat, eggs,”^23^ “high traditional,”^11^ “fish, poultry, and vegetables based,”^8^ “vegetable, fruit, and white rice,”^7^ and “milk, pasta, white bread, shellfish, vegetable and olive oils, sweets, fruit juices, dipping sauces, salty snacks, fries.”^2^ The most common components included vegetables, grains, and fish and seafood; however, the inclusion of other foods and beverages, such as fruits, meats, eggs, dairy, added sugars, were more variable across the dietary patterns. Additionally, some of the dietary patterns were difficult to interpret due to the description of few components.^23,47^

Most of the observational studies (21 articles that included data from 23 PCS) reported that 1 or more dietary patterns were not significantly associated with risk of LGA.^1,3,7,8,10–14,18,22,23,25,27,35,36,38,46–49^ The indices and scores predominantly emphasized similar foods and beverages, including vegetables, fruits, whole grains, legumes, nuts, and unsaturated fatty acids as positive components and red and processed meats, added sugars, saturated fats, and sodium as negative components.^3,10,13,14,18,35,36,38,46,48^ Despite the similarities of the dietary patterns assessed in these studies, there were not consistent trends in the direction of the non-significant associations, with some studies trending towards lower risk of LGA,^10,13,18,36,38,48^ some trending towards higher risk of LGA,^3,46^ and others without a clear directional trend or minimal differences in risk.^14,35,38,46^ A larger proportion of the dietary patterns with non-significant associations were determined via a posteriori methods including factor/cluster analysis^3,7,8,11,12,23,25,27,46,47,49^ and reduced rank regression.^1,22^ These dietary patterns were more varied than those described by indices and scores. But, similarly, trends in the directionality of the non-significant associations were also variable among these studies, with some dietary patterns trending towards lower risk of LGA,^1,8,11,12,22,25,46,47^ some towards higher risk of LGA,^7,8,11,12,23,25,27,47,49^ and some without a clear directional trend or minimal differences in risk.^1,3,22,23,25,46,47^ Additionally, the limited description of or limited components in some of the dietary patterns made the interpretability of some dietary patterns difficult.^12,23,25,46,47^

### Low birth weight

Six dietary patterns reported in 6 articles from 5 unique cohorts were significantly associated with lower risk of LBW. Although the foods and food groups varied between dietary patterns, they were commonly characterized by higher intakes of vegetables, fruits, legumes, whole grains, fish/seafood, dairy, and unsaturated fats, as well as lower intakes of added sugars and saturated fats. One dietary pattern reported in 1 article was significantly associated with higher risk of LBW. Twenty-one dietary patterns reported in 12 articles from 12 unique trials or cohorts did not significantly affect or were not significantly associated with risk of LBW. A summary of the findings is included below, with detailed information presented in Table 8.

#### Intervention studies

Only 1 RCT examined the effect of dietary patterns consumed during pregnancy and risk of LBW: the OPTIMISE RCT conducted in Australia.^55^ In this trial, a lifestyle intervention that provided dietary advice consistent with current Australian dietary standards did not have a significant effect on risk of LBW relative to participants who received standard antenatal care. Although the results trended in the direction of higher risk of LBW in the intervention group, the confidence interval was imprecise.

#### Observational studies

Fifteen articles from 14 PCS examined the relationship between dietary patterns consumed during pregnancy and risk of LBW.^10,14–16,18,30,31,33,34,37,40,43,45,46,50^

Of these, 6 articles from 5 PCS detected a significant association between alignment with a dietary pattern and lower risk of LBW. All 5 articles used an index or score to define the dietary pattern. These scores included: HEI-2015^30,31^; Alternative Healthy Eating Index^37^; a Mediterranean-style diet^46^; the Maternal Diet Quality Score^50^; and a balanced diet score based on recommendations from Japanese dietary guidelines.^33^ The dietary components emphasized across these patterns were relatively similar, with all or most studies emphasizing vegetables, fruits, whole grains, legumes, fish and seafood, and unsaturated fats as positive components, as well as saturated fats as negative components.

In contrast, 1 article from 1 PCS detected a significant association between alignment with a “western” dietary pattern, derived from factor/cluster analysis, and higher odds of LBW.^16^ This dietary pattern was characterized by higher intakes of juice, processed meats, high-fat dairy, added sugars, and saturated fats, but was also characterized by higher intakes of vegetables (specifically potatoes), fruits, whole grains, legumes, fish, eggs, and nuts, and lower intakes of refined grains.

Eleven articles from 11 PCS reported that 1 or more dietary patterns were not significantly associated with risk of LBW.^10,14–16,18,34,40,43,45,46,50^ Seven studies assessed dietary patterns via indices or scores, primarily emphasizing similar dietary components, including vegetables, fruits, whole grains, legumes, nuts and seeds, and unsaturated fats as positive components and red and processed meat, added sugars, saturated fats, and sodium as negative components^10,14,18,40,43,45,46^; however 1 study also examined a “junk food score” which included processed meat, soft drinks, fast food, and chips as positive components.^43^ The trends across these studies were variable, with some dietary patterns trending towards higher risk of LBW,^18,43^ some dietary patterns trending towards lower risk,^40,45,46^ and some dietary patterns with minimal differences or mixed results across levels of alignment.^10,14,43^ Five studies assessed dietary patterns via factor/cluster analysis; the foods and beverages emphasized across the dietary patterns analyzed were variable, with the most common components being vegetables, followed by grains, fruits, meats, and fish and seafood.^15,16,34,46,50^ Among these, the dietary patterns that trended towards lower risk of LBW most commonly emphasized higher intakes of vegetables, fruits, whole grains, white and lean meat, and fish and seafood,^15,46,50^ while the dietary patterns that trended towards higher risk of LBW most commonly emphasized higher intakes of vegetables, refined grains, red and processed meats, and added sugars.^15,16,46,50^ One study directly compared dietary patterns to each other, limiting comparability to the other studies that identified dietary patterns via factor/cluster analysis.^34^

### Macrosomia

Four dietary patterns reported in 4 articles from 4 unique cohorts were significantly associated with lower risk of macrosomia. Although the foods and food groups varied between dietary patterns, most were characterized by higher intakes of vegetables and fruits, and lower intakes of added sugars. Three dietary patterns reported in 3 articles from 3 unique cohorts were significantly associated with higher risk of macrosomia. Twenty-four dietary patterns reported in 13 articles from 12 unique trials or cohorts were not significantly affected or significantly associated with risk of macrosomia. A summary of the findings is included below, with detailed information presented in Table 8.

#### Intervention studies

Only 1 RCT examined the effect of dietary patterns consumed during pregnancy and risk of macrosomia: the OPTIMISE RCT conducted in Australia and described previously.^55^ In this trial, the lifestyle intervention did not have a significant effect on risk of macrosomia relative to standard antenatal care. Although the results trended in the direction of lower risk of macrosomia, the confidence interval was imprecise.

#### Observational studies

Fourteen articles from 13 PCS examined the relationship between dietary patterns consumed during pregnancy and risk of macrosomia.^8,10,12,14,18,19,30,31,34,40,43,45–47^

Of these, 4 articles from 4 PCS detected a significant association between alignment with a dietary pattern and lower risk of macrosomia.^18,43,45,47^ Three utilized indices or scores, which included: the HEI-2010^45^; the Norwegian Fit for Delivery diet^18^; and a dietary behavior score based on meeting Australian dietary recommendations.^43^ Among these dietary patterns, 2 were associated with lower risk of birth weight greater than 4,000 g,^43,45^ and the other was associated with lower risk of birth weight greater than 4,500 g and prior to statistical adjustment for physical activity^18^; after adjustment for physical activity, as well as for analyses using a cut-off of 4,000 g, associations were no longer statistically significant.^18^ Components of the indices/scores that were consistent across studies included vegetables and fruits as positive components as well as added sugars and sodium as negative components. The fourth PCS used factor/cluster analysis to derive the dietary pattern and found that alignment with a “nuts, aquatic products, snacks” dietary pattern was associated with lower risk of birth weight greater than 4,000 g.^47^

Three articles from 3 PCS detected a significant association between alignment with a dietary pattern and higher risk of macrosomia.^19,43,47^ The first comprised a “dietary risk score,” which was based on [underlined: not] following Icelandic and Nordic dietary recommendations, and was associated with higher risk of birth weight greater than 4,500 g overall and among participants with pre-pregnancy BMI less than 25.^19^ The second comprised a “junk food score,” which was based on consumption of processed meat, soft drinks, fast food, and chips, and was associated with higher risk of birth weight greater than 4,000 g, consistent with analyses from the same study relating a dietary behavior score based on Australian dietary recommendations and risk of macrosomia.^43^ These 2 studies emphasized some similar components to those reporting a significant association between dietary patterns and lower risk of macrosomia, however with reversed directionality such that the results are consistent with each other. Specifically, these studies both included processed meat and added sugars as positive components,^19,43^ while 1 included vegetables and fruits (among other food groups) as negative components.^43^ In contrast, the final study used factor/cluster analysis to derive a “cereals, vegetables, fruits” dietary pattern which was associated with higher risk of birth weight greater than 4,000 g.^47^

Twelve articles from 11 PCS reported that 1 or more dietary patterns were not significantly associated with risk of macrosomia.^8,10,12,14,18,19,30,31,34,46,47^ Among studies utilizing indices or scores, most emphasized vegetables, fruits, whole grains, legumes, and unsaturated fats as positive components and red and processed meats, added sugars, saturated fats, and sodium as negative components^10,14,18,30,31,46^; 1 used a score that, broadly, reversed the directionality of these components.^19^ The direction of trends varied among these dietary patterns, despite emphasizing similar components, with some associated with lower risk of macrosomia^10,18,19^ and others associated with higher risk of macrosomia.^14,30,31,46^ Studies that identified dietary patterns via factor/cluster analysis varied in regards to the components included in each dietary pattern.^15,16,34,46^ Additionally, there were not consistent trends among the dietary patterns, with associations trending both toward lower^8,12,47^ and higher^8,12,34,46,47^ risk of macrosomia regardless of the general composition of the dietary pattern.

## Conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee developed 2 conclusion statements to answer the question, “What is the relationship between dietary patterns consumed during pregnancy and birth weight?” based on their review of the body of evidence. A conclusion statement was drawn regarding the risk of SGA (Table 6), while a conclusion statement was not drawn regarding the risk of LGA, LBW, and macrosomia (Table 7).

### Small-for-gestational age

The Committee’s conclusion statement regarding the relationship between dietary patterns consumed during pregnancy and risk of SGA is presented in Table 6. The risk of bias assessments for all studies are documented in Table 9, Table 10, and Table 11, for RCT, NRCT, and PCS, respectively.

Table 6 Conclusion statement, grade for dietary patterns consumed during pregnancy and small-for-gestational age

Conclusion Statement | Dietary patterns consumed during pregnancy that are characterized by higher intakes of vegetables, fruits, legumes, nuts and seeds, grains, fish/seafood, dairy, and unsaturated fats, and lower intakes of red and processed meat, added sugars, and saturated fats may be associated with lower risk of small-for-gestational age in infants. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 49 articles: 8 randomized controlled trials, 1 non-randomized controlled trial, 42 prospective cohort studies
Consistency | The results showed some inconsistency in the direction and magnitude of effects and associations across both significant and non-significant results. Inconsistencies were most prominent for prospective cohort studies, particularly those that analyzed dietary patterns identified via a posteriori methods.
Precision | There were concerns regarding precision in this body of evidence. Few studies were specifically powered to detect differences in small-for-gestational age and most prospective cohort studies did not report power. Variance around the effect estimates were variable, including some studies with relatively wide confidence intervals.
Risk of bias | Most prospective cohort studies had an overall high risk of bias due to confounding, missing data, selection of participants, exposure measurement, and selection of the reported result. Half of the trials had some concerns or high overall risk of bias due to deviations from intended interventions and selection of the reported result.
Directness | The body of evidence had substantial concerns with directness. Most studies were not designed to directly examine the relationship between dietary patterns and risk of small-for-gestational age.
Generalizability | There was limited generalizability of the studies to the U.S. population when considering study and participant characteristics including country, socioeconomic position, and dietary patterns. However, among studies conducted in the United States, there was more diversity in race and/or ethnicity.

#### Assessment of the evidence

The body of evidence underlying the graded conclusion statement on risk of SGA includes 49 articles from 8 RCT, 1 NRCT, 42 PCS. The evidence was graded based on an assessment of 5 grading elements, as described below. Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence included studies that reported only non-significant findings, only significant findings, and a mix of both significant and non-significant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

##### Consistency

Among the trials, there was inconsistency in results, with approximately half detecting no significant effect of dietary patterns consumed during pregnancy on risk of SGA and half detecting an effect of dietary patterns consumed during pregnancy on reduced risk of SGA, either overall or in a sub-group of the full study sample.

However, those trials that did not detect a significant effect of dietary patterns mostly trended toward a beneficial effect on SGA, with none clearly trending toward higher risk of SGA. These dietary patterns tended to emphasize similar foods: vegetables, fruits, legumes, fish/seafood, nuts and seeds, unsaturated fats as positive components and red and processed meats, added sugars, and saturated fats as negative components. But, most trials focused on EVOO and nuts as the dietary intervention, which may have driven the differences in dietary pattern adherence between groups.

The pattern of results for the PCS were similar to the trials, however, inconsistency was more pronounced. The PCS that used indices or scores to evaluate dietary patterns showed some inconsistency in magnitude of association, but the directionality of both significant and non-significant associations, as well as the food and beverages emphasized across the patterns, were relatively consistent. Specifically, most of these dietary patterns were significantly associated with or trended towards lower risk of SGA and emphasized vegetables, fruits, grains, legumes, fish/seafood, dairy, and nuts and seeds as positive components and red and processed meat, added sugars, and saturated fats as negative components. Among the dietary patterns identified via a posteriori methods, alignment with some patterns were associated with lower risk of SGA, while few studies detected a statistically significant association between a posteriori identified dietary patterns and higher risk of SGA. However most dietary patterns identified via a posteriori methods were not significantly associated with the risk of SGA; a range of individual food and beverage components were represented across these dietary patterns, and the trends were mixed.

##### Precision

Relatively few intervention studies were included in the body of evidence. Although 1 trial was specifically powered to detect between-group differences in SGA,^54^ the other included trials were powered for a different infant or pregnancy-related outcome. Among the trials, analytic sample sizes ranged from 196 to 1,095 participants, with over half including at least 500 participants. A larger pool of PCS that assessed SGA were identified compared to trials. Power analyses were not typically reported for the PCS, and when they were provided, they were not specific to SGA. Analytic sample sizes ranged widely from 94 to 72,317 participants, but over half included at least 1,000 participants. Across both intervention and observational studies, approximately 2.5% to 30.5% of infants were born SGA, with most studies reporting that ≤15% were born SGA.

##### Risk of bias

Among the RCT, approximately half had concerns in regard to selection of the reported result and deviations from the intended intervention. Risk of bias due to randomization, missing outcome data, and outcome measurement was predominantly assessed as low. The NRCT had several risk of bias concerns including from confounding, classification of interventions, deviations from intended interventions, and selection of the reported result.

Among the PCS, most studies had high risk of bias due to missing data and some concerns due to selection of the reported result, confounding, and selection of participants. Approximately half of the PCS had concerns regarding risk of bias due to post-exposure interventions. Risk of bias due to exposure measurement among the PCS varied, with some studies using validated dietary assessment early or throughout in pregnancy and others using unvalidated or non-standard assessments later in pregnancy. Risk of bias due to outcome measurement across all PCS was low.

##### Directness

Across both trials and cohort studies, SGA was predominantly not the primary outcome of interest. However, most studies were designed to assess a variety of pregnancy-related outcomes and/or infant outcomes at birth. The RCT and NRCT were directly designed to assess the effect of dietary patterns during pregnancy on these outcomes. But, in 2 trials, dietary advice to consume a Mediterranean-style diet was given to both the intervention and control groups, with the primary difference between groups being the provision of and/or recommendation to consume EVOO and nuts to the intervention group, rather than a more meaningful difference in dietary patterns between groups.^52,53,58,60^ The observational studies were generally designed to examine a variety of exposures during pregnancy, although not specifically dietary patterns.

##### Generalizability

Only 2 trials were conducted in the United States,^56,59^ with the majority of the other trials conducted in Western Europe. Participants in these trials predominantly had some college education, were employed, had at least a “middle class” income, and/or had a pre-pregnancy BMI less than 25. Participants were predominantly White, but individuals of some other races and/or ethnicities were represented across the trials. The generalizability of some trials was limited by the type of dietary pattern tested. As noted previously, half of the trials focused on a Mediterranean-style diet, and specifically on EVOO and nuts.^51–54,58,60^

Ten articles from 9 PCS were conducted in the United States,^3,10,13,14,24,27,36,38,46,48^ while the remaining studies were predominantly conducted in Western Europe and Asia. Although the majority of PCS reported that participants predominantly had some college education, were employed, had at least a “middle class” income, and/or had a pre-pregnancy BMI less than 25, there was variation across the studies in regard to these characteristics. Similarly, although the most commonly represented racial and/or ethnic group was White, participants who were Hispanic and/or Latino, Black and/or African American, or Asian were also represented across the PCS. American Indian, Alaska Native and Native Hawaiian participants were not well represented across the PCS. Finally, a variety of dietary patterns were assessed across the studies, using both a priori and a posteriori methods.

### Large-for-gestational age, low birth weight, and macrosomia

The Committee did not draw a conclusion statement about the relationship between consumption of dietary patterns during pregnancy and risk of LGA, LBW, and macrosomia (Table 7). The risk of bias assessments for all studies are documented in Table 9, Table 10, and Table 11, for RCT, NRCT, and PCS, respectively.

Table 7 Conclusion statement, grade for dietary patterns consumed during pregnancy and large-for-gestational age, low birth weight, and macrosomia

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during pregnancy and risk of large-for-gestational age, low birth weight, and macrosomia in infants because of substantial concerns with consistency, risk of bias, and generalizability in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 45 articles: 8 randomized controlled trials, 1 non-randomized controlled trials, 36 prospective cohort studies
Rationale | The direction and magnitude of results were inconsistent; additionally, there was variability in the dietary patterns assessed, particularly those identified via a posteriori methods. Most studies had multiple risk of bias concerns, as well as high overall risk of bias. Generalizability of the body of evidence to the U.S. population, both in terms of participant characteristics and the dietary patterns, was limited.

This was due to substantial concerns with consistency, risk of bias, and generalizability in the body of evidence. Additionally, only 1 trial examined LBW and macrosomia, further limiting the ability to draw a conclusion statement. Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence included studies that reported only non-significant findings, only significant findings, and a mix of both significant and non-significant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.