# Plain language summary

### What is the question?

The question is: What is the relationship between dietary patterns consumed during pregnancy and birth weight? The populations of interest for this question include individuals during pregnancy.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team. This review updated an existing review that was conducted as part of the Pregnancy and Birth to 24 Months Project.

### What is the answer to the question?

- Dietary patterns consumed during pregnancy that are characterized by higher intakes of vegetables, fruits, legumes, nuts and seeds, grains, fish/seafood, dairy, and unsaturated fats, and lower intakes of red and processed meat, added sugars, and saturated fats may be associated with lower risk of small-for-gestational age in infants. This conclusion statement is based on evidence graded as limited.
- A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during pregnancy and risk of large-for-gestational age, low birth weight, and macrosomia in infants because of substantial concerns with consistency, risk of bias, and generalizability in the body of evidence.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 1980 and January 2024.