# Appendix 6 Dietary pattern visualization

The Committee’s synthesis was facilitated by a data visualization table that presented the dietary pattern components in each of the dietary patterns examined in the body of evidence (Table A 9). During evidence synthesis, these tables were used in conjunction with other materials to compare and contrast the components in the dietary patterns studied along with the direction, magnitude, and statistical significance of reported results. Detailed information about the synthesized body of evidence, including study and population characteristics, reported results for all relevant outcomes, key confounders accounted for, and funding sources, are summarized in the evidence tables of this report (Table 5 and Table 8).

Each column represents the most commonly reported foods/food groups or nutrients across dietary patterns in this body of evidence. Two additional columns, “Other A” and “Other B”, captured a variety of other components less frequently reported across dietary patterns that did not fit into one of the preceding columns or categories, such as fast food, ready-to-eat dishes, and pizza. Empty cells mean that the dietary pattern did not include a component within that column/category.

Table A 9 Visualization of dietary pattern components organized by approach across evidence examining the relationship between dietary patterns consumed during pregnancy and birth weight^*^,^†^

Article; Dietary pattern | Vegetables | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains | Grains: Whole | Grains: Refined | Fish, Seafood | Meats: Red, Processed | Meats: Lean, Poultry | Eggs | Dairy | Dairy: Low, Non-fat | Dairy: Whole, High-fat | SSB | Sugary Foods | Fats | Fats: Unsaturated, Oils | Fats: Saturated | Alcohol | Tea and Coffee | Sodium | Other Nutrients | Other A | Other B
RCT
Al Wattar, 2019^51^; Mediterranean-style diet | ▲ | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | | ▲ OO | ▼
Assaf-Balut, 2017^52^; Mediterranean-style DP supplemented w/ pistachios and EVOO | ▲ | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | | ▲ OO | ▼ | ▲ Wi
Assaf-Balut, 2019^53^; Mediterranean-style DP supplemented w/ pistachios and EVOO | ▲ | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | | ▲ OO | ▼ | ▲ Wi
Crovetto, 2021^54^; Mediterranean-style diet supplemented w/ walnuts and EVOO | ▲ | ▲ | ▲ | | ▲ N | | ▲ | ▼ | ▲ F | ▼ RP | ▲ W | | ▲ | | | ▼ | ▼ | | ▲ OO | ▼
Dodd, 2019^55^; Lifestyle intervention with dietary advice consistent with Australian dietary standards | ▲ | | ▲ | | | | | | | | | | ▲
Gallagher, 2018^56^; Lifestyle intervention with higher HEI-2010 alignment | ▲ | ▲ pro | ▲ | Fr | pro | | ▲ | ▼ | ▲ S | pro | pro | pro | ▲ | | | ▼ AS | AS | | ▲ FA | ▼ Solid fats | ▼ | | ▼
Khoury, 2005^57^; Cholesterol-lowering diet advice | ▲ | | ▲ | | ▲ | | | | ▲ F | ▼ M | ▼ M | | | | ▼ | | | | ▲ | ▼ | | | | | ▲
Melero, 2020^58^; Mediterranean-style DP w/ recommended additional pistachios and EVOO | ▲ | ▲ | | | ▲ N | | | | ▲ F | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | | ▲ OO | ▼
Van Horn, 2018^59^; Calorie-controlled, DASH-type diet and lifestyle intervention | ▲ | ▲ | ▲ | Fr | ▲ N | | ▲ | | | ▼ RP | | | | ▲ | | ▼ | | | | | | | ▼
Zhao, 2022^60^; Mediterranean-style DP w/ recommended additional pistachios and EVOO | ▲ | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | | ▲ OO | ▼ | ▲ Wi
NRCT
Melero, 2020^58^; Mediterranean-style DP w/ recommended additional pistachios and EVOO | ▲ | ▲ | | | ▲ N | | | | ▲ F | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | | ▲ OO | ▼
Index/Score
Ancira-Morena, 2020^50^; MDQS | ▲ | ▲ | ▲ | | | | | | | ▼ R | | | | ▲ | | ▼ AS | AS | | ▲ PUFA
Berube, 2023^3^; HEI-2015 | ▲ | ▲ pro | ▲ | Fr | pro | | ▲ | ▼ | ▲ S | pro | pro | pro | ▲ | | | ▼ AS | AS | | ▲ FA | ▼ SFA | | | ▼
Chatzi, 2012^5^; Mediterranean Diet | ▲ | ▲ | ▲ | | ▲ N | ▲ | | | ▲ | ▼ M | M | | ▲ | | | | | | ▲ MUFA:SFA | MUFA:SFA
Chen, 2021^6^; ALPHABET DASH | ▲ | ▲ | ▲ | | LNS | ▲ | | | | ▼ RP | | | | ▲ | | ▼ | ▼ | | | | | | ▼
Díaz-López, 2022^9^; Relative MedDiet | ▲ | ▲ | ▲ | | | ▲ | | | ▲ F | ▼ M | M | | ▲ | | | | | | ▲ OO | | ▼
Emond, 2018^10^; AHEI-2010 | ▲ | ▲ | ▲ | | ▲ N | | ▲ | | | ▼ RP | | | | | | ▼ | | | ▲ n-3 FA, PUFA | ▼ Trans fat | | | ▼
Fulay, 2018^13^; DASH OMNI | ▲ | ▲ | ▲ | ▲ | ▲ N | | ▲ | | | ▼ RP | | | | ▲ | | ▼ | | | ▲ PUFA, MUFA | | | | ▼
Fulay, 2018^13^; DASH | ▲ | ▲ | ▲ | ▲ | ▲ N | | ▲ | | | ▼ RP | | | | ▲ | | ▼ | | | | | | | ▼
Gonzalez-Nahm, 2019^14^; AHEI-2010 | ▲ | ▲ | ▲ | | ▲ N | | ▲ | | | ▼ RP | | | | | | ▼ | | | ▲ n-3 FA, PUFA | ▼ Trans fat | | | ▼
Hillesund, 2014^17^; New Nordic Diet | ▲ | | ▲ | ▼ | | | ▲ | ▼ | ◄ F | ◄ | ◄ | | ▲ | | | ▼ | | | | | | | | | ▲
Hillesund, 2018^18^; NFFD Diet | ▲ | | ▲ | | | | | | | | | | | | | ▼ AS | AS | | | | | | ▼ | | ▲ | ▼
Hrolfsdottir, 2019^19^; Dietary Risk Score | ◄ | ▼ | ▼ | | ▼ | | ▼ | | ▼ F | ▲ P | | | ◄ | | | ▲ | ▲ | | ▲ Other UFA sources rather than oil | ▲ | | | | ▼ Vit D | ▲
Lipsky, 2023^24^; HEI-2015 | ▲ | ▲ pro | ▲ | Fr | pro | | ▲ | ▼ | ▲ S | pro | pro | pro | ▲ | | | ▼ AS | AS | | ▲ FA | ▼ SFA | | | ▼
Makarem, 2022^26^; aMED | ▲ | ▲ | ▲ | | ▲ N | | ▲ | | ▲ F | ▼ RP | | | | | | | | | ▲ MUFA:SFA | MUFA:SFA | ◄
Navarro, 2019^31^; HEI-2015 | ▲ | ▲ | ▲ | Fr | | | ▲ | ▼ | ▲ S | ▲ pro | pro | | ▲ | | | ▼ AS | AS | | ▲ PUFA + MUFA:SFA | ▼ SFA
Navarro, 2020^30^; HEI-2015 | ▲ | ▲ | ▲ | Fr | | | ▲ | ▼ | ▲ S | ▲ pro | pro | | ▲ | | | ▼ AS | AS | | ▲ PUFA + MUFA:SFA | ▼ SFA
Okubo, 2023^33^; Balanced Diet Score | ▲ | | ▲ | | | ▲ | | | ▲ F | ▲ M | M | | ▲ | | | | | | | | ▼ | | ▼ | | ▼
Parisi, 2020^35^; FIGO | ▲ | | ▲ | | | | ▲ | | ▲ F | ▲ M | M | | ▲ | | | | ▼ | | | | | | ▲ | ▲ Folic acid | ▲ | ▼
Poon, 2013^36^; aMED | ▲ | ▲ | ▲ | | ▲ N | | ▲ | | ▲ F | ▼ RP | | | | | | | | | ▲ MUFA:SFA | MUFA:SFA
Poon, 2013^36^; AHEI-P | ▲ | ▲ | ▲ | | ▲ N | | ▲ | | | ▼ RP | | | | | | ▼ | | | ▲ n-3 FA, PUFA | ▼ Trans fat | | | ▼ | ▲ Ca, Fe, Folate
Reyes-López, 2021^37^; AHEI-2010 for Pregnancy | ▲ | ▲ | ▲ | ▼ | ▲ N | | ▲ | | ▲ F | ▼ RP | | | | | | ▼ | | | ▲ PUFA | ▼ Trans fat | | | | ▲ Ca, Fe, Folate
Rifas-Shiman, 2009^38^; AHEI-P | ▲ | | ▲ | | | | | | ▲ W:R | W:R | W:R | | | | | | | | ▲ PUFA:SFA | ▼ Trans fat | | | | ▲ Ca, Fe, Folate | ▲
Rodriguez-Bernal, 2010^39^; AHEI-P | ▲ | ▲ | ▲ | | LN | | | | ▲ W:R | W:R | W:R | | | | | | | | ▲ PUFA:SFA | ▼ Trans fat | | | | ▲ Ca, Fe, Folate | ▲
Santos, 2021^40^; IQDAG | ▲ | ▲ | ▲ | | | | | | | | | | | | | | | | ▲ n-3 FA | | | | | ▲ Ca, Fe, Folate | ▲ | ▼
Sun, 2023^41^; Dietary Diversity Score | ▲ | ▲ | ▲ | | ▲ | ▲ | | | ▲ F | ▲ M | M | ▲ | ▲
Xu, 2023^43^; Dietary Behavior Score | ▲ | | ▲ | | | | | | | ▼ P | | | | | | ▼ | | | | | | | | | ▼
Xu, 2023^43^; Junk Food Score | | | | | | | | | | ▲ P | | | | | | ▲ | | | | | | | | | ▲
Yee, 2020^45^; HEI-2010 | ▲ | ▲ pro | ▲ | Fr | pro | | ▲ | ▼ | ▲ S | pro | pro | pro | ▲ | | | ▼ AS | AS | | ▲ FA | ▼ Solid fats | ▼ | | ▼
Yisahak, 2021^46^; AHEI-2010 | ▲ | ▲ | ▲ | | ▲ N | | ▲ | | | ▼ RP | | | | | | ▼ | | | ▲ PUFA | ▼ Trans fat | | | ▼
Yisahak, 2021^46^; DASH | ▲ | ▲ | ▲ | | ▲ | | ▲ | | | ▼ RP | | | | ▲ | | ▼ | | | | | | | ▼
Yisahak, 2021^46^; aMed | ▲ | ▲ | ▲ | | ▲ N | | ▲ | | ▲ F | ▼ RP | | | | | | | | | ▲ MUFA:SFA | MUFA:SFA
Zhu, 2019^48^; HEI-2010 | ▲ | ▲ pro | ▲ | Fr | pro | | ▲ | ▼ | ▲ S | pro | pro | pro | ▲ | | | ▼ AS | AS | | ▲ FA | ▼ Solid fats | | | ▼
Factor/Cluster
Ancira-Morena, 2020^50^; Healthier | ▲ | ▼ | ▲ | | | ▲ | | | | | ▲ W | ▲ | | ▲ | | ▼ | ▼ | | | ▼
Ancira-Morena, 2020^50^; Mixed | ▲ | | | | | ▲ | | | | ▲ RP | ▼ W | ▼ | | | | ▲ | ▼ | | ▼ | ▼ | | | | | ▲
Barchitta, 2023^2^; Milk, pasta, white bread, shellfish, vegetable and olive oils, sweets, fruit juices, dipping sauces, salty snacks, fries | ▲ | | | ▲ | | ▲ | | ▲ | ▲ S | | | | ▲ | | | | ▲ | | ▲ | | | | ▲ | | ▲
Berube, 2023^3^; Western | | | | | | | | | | ▲ P | | | | | | ▲ | ▲ | | | | | | ▲ | | ▲
Berube, 2023^3^; Fruits and vegetables | ▲ | ▲ | ▲ | | | | | | | | | | | | | | | | | | | | | | ▲
Bodnar, 2023^4^; High fruits, vegetables, whole grains, and plant proteins | ▲ | ▲ | ▲ | | ▲ | | | | | | | | ▲ | | | | | ▲ Salad dressing | | | | ▲ C
Bodnar, 2023^4^; Sandwiches and snacks | | | | | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | ▲ | ▲ | ▲ | ▲ Salad dressing | | | ▲ | ▲ C | | | ▲
Bodnar, 2023^4^; Beverages, refined grains, and mixed dishes | ▲ | ▲ | | ▲ | | ▲ | | | | ▲ | | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | | | | | ▲
Chia, 2016^7^; Vegetable, fruit, and white rice | ◄ | | ▲ | | ▲ | | ▲ | ◄ | ▲ F | ▲ | | | | | | ▲
Chia, 2016^7^; Seafood and noodle | | ▲ | | | | ◄ | | ▼ | ▲ | ▲ R | | | | | | | | | | | | | | | ▲ | ▼
Chia, 2016^7^; Pasta, cheese, and processed meat | ▲ | | | | | ▲ | | | | ▲ P | | | | | ▲
de Seymour, 2022^8^; Fish, poultry, and vegetable-sbased | ▲ | ▲ | ▲ | | ▲ N | ▲ | | | ▲ | ▲ | ▲ | ▲ | ▲ | | | | | | | | | | | | ▲
de Seymour, 2022^8^; Pasta, sweetened beverages, oils, and condiments-based | | | | | | ▲ | | | | | | | | | | ▲ | | ▲ Oils and condiments | | | | | | | ▲
Englund-Ogge, 2019^11^; High prudent | ▲ | | ▲ | | ▲ N | | ▲ | ▼ | | ▼ RP | ▲ | | | | | | | | | | | | | | ▲ | ▼
Englund-Ogge, 2019^11^; High traditional | ▲ | | | | | | | | ▲ F | | ▼ | | | ▲ | | | ▲ | ▲ Margarine | | | | | | | ▲ | ▼
Flynn, 2016^12^; African/ Caribbean | ▲ | | ▲ | | | | ▲ | ▲ | ▲ F | ▲ R | ▲ W
Flynn, 2016^12^; Fruit and vegetable | ▲ | ▲ | ▲ | | | | | | | | | | ▲
Flynn, 2016^12^; Processed | ▲ | | | | | | | | | ▲ P | | | | | | ▲ | ▲ | | | | | | | | ▲
Flynn, 2016; Snacks | | | | | | | | | | | | | | | ▲ | | ▲
Grieger, 2014^15^; High protein, fruit | | | ▲ | | | | ▲ | | ▲ F | ▲ | ▲
Grieger, 2014^15^; High-fat/sugar/takeaway | | | | | | | | ▲ | | | | | | | | ▲ AS | AS | | | | | | | | ▲
Grieger, 2014^15^; Vegetarian-type | ▲ | ▲ | | | | | ▲
Hajianfar, 2018^16^; Western | ▲ | ▲ | ▲ | ▲ | ▲ N | | ▲ | ▼ | ▲ F | ▲ P | | ▲ | | | ▲ | ▲ | ▲ | | | ▲ | | ▲ C | | | ▲
Hajianfar, 2018^16^; Healthy | ▲ | | ▲ | | ▲ N | | | | ▲ F | ▲ R | ▲ | ▲ | | ▲ | | | | | ▲ Olives, marinades, and unsaturate d fat
Hajianfar, 2018^16^; Traditional | ▲ | | | | | | | ▲ | | | | | | | | ▲ AS | AS | | ▲ Olives and unsaturate d fat | | | ▲ T | ▲ | | ▲
Knudsen, 2008^21^; Health conscious | ▲ | | ▲ | | | ▲ | | | ▲ F | ▼ | ▲ | | | | | | | | | ▼ | | | | | ▲
Knudsen, 2008^21^; Intermediate | | | | ▲ | | | | | | | | | | ▲
Li, 2021^23^; Beans-vegetables | ▲ | ▲ | ▲
Li, 2021^23^; Fish-meat-eggs | | | | | | | | | ▲ F | ▲ R | | ▲
Li, 2021^23^; Nuts-whole grains | | | | | ▲ N | | ▲ | | | | | | ▲
Li, 2021^23^; Organ-poultry-seafood | | | | | | | | | ▲ S | ▲ | ▲
Li, 2021^23^; Rice-wheat-fruits | | | ▲ | | | ▲
Lu, 2016^25^; Varied | ▲ | ▲ | | | | ▲ | | | ▲ | ▲ | ▲ | | ▲ | | | ▲ | ▲ | | | | | | | | ▲
Lu, 2016^25^; Dairy | ▼ | | | | | | | | | | | | ▲
Lu, 2016^25^; Meats | | | | | | | | | | ▲ RP
Lu, 2016^25^; Fruits, nuts, and Cantonese desserts | | | ▲ | | ▲ N | | | | | | | | | | | | ▲
Lu, 2016^25^; Vegetables | ▲
Maldonado, 2022^27^; Vegetables, oils, fruit | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | ▲ S | ▲ RP | ▲ | ▲ | ▲ | | | ▲ AS | AS | | ▲ | ▼ Solid fats
Maldonado, 2022^27^; Solid fat, refined grain, cheese | ◄ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▲ | ▲ S | ▲ RP | ▲ | ▲ | ◄ | | | ▲ AS | AS | | ▲ | ▲ Solid fats
Miele, 2021^28^; Intermediate | | | | | | | | ▼ | | | | | | | | | ▼ | ▼ Fats | | | | | | | ▼
Miele, 2021^28^; Protein | ▲ | ▲ | | | | | | | | ▲ | | ▲ | | | | | | | | | | | | | ▼
Miele, 2021^28^; Vegetarian | ▲ | | ▲ | | | | | | | | | | ▲
Miele, 2021^28^; Obesogenic | | | | | | | | ▲ | | | | | | | | | ▲ | ▲ Fats | | | | | | | ▲
Mikeš, 2022^29^; Unhealthy | ▲ | | | | | ▲ | | | ▲ F | ▲ | ▲ | ▲ | | | | ▲ | ▲ | | | | | | | | ▲
Mikeš, 2022^29^; Healthy/traditional | ▲ | | ▲ | ▲ | | | ▲ | ▲ | | | | | ▲ | | | | ▲ | | | | | ▲ T
Okubo, 2012^32^; Meat and eggs | | | | | | | | | | ▲ RP | ▲ | ▲ | ▲ | | | | | | | ▲
Okubo, 2012^32^; Wheat products | | | | ▲ | | ▲ | | | | | | | | | | ▲ | ▲
Paknahad, 2019^34^; High carbohydrate-lower fat | ▲ | ▲ | ▲ | | | ▲ | | | | | | ▲ | | ▲ | | | | | | | | | | | ▲
Paknahad, 2019^34^; High carbohydrate-higher fat | ▲ | ▲ | | | | | | | ▲ F | | | | | | ▲ | | | | | ▲ | | | | | ▲
Teixeira, 2021^42^; Lentils, whole grains, and soups | | ▲ | ▲ | | LN | | ▲ | ▼ | | ▲ | | | ▲ | | ▲ | ▲ | ▲ | | | | | | | | ▲
Teixeira, 2021^42^; Snacks, sandwiches, sweets, and soft drinks | ▲ | | | | | | | | | ▲ RP | ▲ | ▲ | ◄ | | | ▲ | ▲ | | | | ▲ | | | | ▲
Teixeira, 2021^42^; Seasoned vegetables and lean meats | ▲ | | ▲ | ▲ | | | | ▲ | ▲ F | | ▲ | | | | | | | | ▲ Oil for salad dressing | | | | ▲ | | ▲
Teixeira, 2021^42^; Sweetened juices, bread and butter, rice, and beans | ▲ | ▲ | | ▼ | | | | ▲ | | | | ▲ | ▲ | | ▲ | ▲ | | | | ▲ | ▼
Yamashita, 2022^44^; Pattern 1 pre-early pregnancy | ▲ | ▲ | ▲ | | | | | | ▲ | | | | ▼
Yamashita, 2022^44^; Pattern 1 early-mid pregnancy | ▲ | ▲ | ▲ | | | | | | ▲ | | | | ▼ | | | | | | | | ▼
Yamashita, 2022^44^; Pattern 2 pre-early pregnancy | ▲ | | | | | ▼ | | | | ▼ M | M | ▲ | ▲
Yamashita, 2022^44^; Pattern 2 early-mid pregnancy | ▲ | ▲ | | | | ▼ | | | | ▼ M | M | ▲ | ▲
Yisahak, 2021^46^; Pattern 1 | ▲ | | | | | | | ▲ | | ▲ R | | | ▲
Yisahak, 2021^46^; Pattern 2 | ▲ | | | | | | | | ▲ S
Zhang, 2023^47^; Cereals-vegetables-fruits | ▲ | | ▲ | | | ▲
Zhang, 2023^47^; Vegetables-poultry-aquatic products | ▲ | | | | | | | | ▲ | ▲ | ▲
Zhang, 2023^47^; Milk-meat-eggs | | | | | | | | | | ▲ R | | ▲ | ▲
Zhang, 2023^47^; Nuts-aquatic products-snacks | | | | | ▲ N | ▲ | | | ▲ | | | ▲ | | | | | ▲ | | | | | | | | ▲
Zulyniak, 2017^49^; Plant-based | ▲ | ▲ | | | | | ▲ | | | ▼ M | M | | ▲ | ▲ | | | | | | | | ▲ T | | | ▲
Reduced-Rank Regression
Alves-Santos, 2019^1^; Fast food and candies | ▼ | ▼ | | | | ◄ | | | | | | | | | | | ▲ | | | | | | | | ▲ | ▼
Alves-Santos, 2019^1^; Vegetables and dairy | ▲ | ▲ | ▲ | ▲ | | ▼ | | | ▲ F | | | | ▲ | | | ▼ | ▲
Alves-Santos, 2019^1^; Beans, bread, and fat | ◄ | ▲ | ▼ | ▼ | | ◄ | | | ▼ F | | | | | | | | ▲ | ▲ Fats used as spreads
Hwang, 2022^20^; Pattern 1 | ▲ | ▲ | ▲ | | ▲ N | ▲ | | | ▲ F | ▲ M | M | ▲ | ▲
Hwang, 2022^20^; Pattern 2 | ▲ | | | | | | | ▼ | | ▼ | ▼
Hwang, 2022^20^; Pattern 3 | | ▼ | | | | ◄ | | | ▼ F | | | | ◄
Lecorguillé, 2020^22^; Varied and balanced | ▲ | | | | | ▲ | | | ▲ F | ▲ M | M | ▲ | | ▲ | | ▼ | ▼ | | | | | | | | ▲ | ▼
Lecorguillé, 2020^22^; Vegetarian tendency | ▲ | | ▲ | | | ▲ | | | | ▼ M | M | | | | | | | | | | | | | | ▲
Lecorguillé, 2020^22^; Bread, starchy food | | | ▼ | ▼ | | ▲ | | | | | | | | ▼ | | ▼ | | | | | | | | | ▲
Yamashita, 2022^44^; RRR pre-early pregnancy | | | ▲ | | | ▲ | | | | | | | | | | | | | | | ▼ | | | | ▼
Yamashita, 2022^44^; RRR early-mid pregnancy | | | ▲ | | | ▲ | | | | | | | ▲ | | | | | | | | ▼ | | | | ▼
Other
Yamashita, 2022^44^; PLS pre-early pregnancy | | | ▲ | | | ▲ | | | | | | | | | | | | | | | ▼ | | | | ▼
Yamashita, 2022^44^; PLS early-mid pregnancy | ▲ | | ▲ | | | ▲ | | | | | | | ▲

* ▲ Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as part of the pattern; ◄ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern.

† Abbreviations: AHEI, Alternative Healthy Eating Index; AHEI-P, Alternative Healthy Eating Index Pregnancy; aMed, Alternative Mediterranean Diet; AS, added sugar; C, coffee; Ca, calcium; DASH, Dietary Approaches to Stop Hypertension; DASH OMNI, DASH Optimal Macronutrient Intake; DP, dietary pattern; EVOO, extra-virgin olive oil; F, fish; FA, fatty acids; Fe, iron; FIGO, International Federation of Gynecology and Obstetrics; Fr, included with Fruit component; HEI, Healthy Eating Index; IQDAG, Diet Quality Index Adapted for Pregnant Women; L, legumes; M, meat; MDQS, Maternal Diet Quality Score; MedDiet, Mediterranean Diet; MUFA, monounsaturated fatty acids; MUFA:SFA, monounsaturated fatty acid-to-saturated fatty acid ratio; MUFA + PUFA:SFA, monounsaturated fatty acid plus polyunsaturated fatty acid-to-saturated fatty acid ratio; N, nuts; n-3, omega-3; NFFD, Norwegian Fit for Delivery; NRCT, non-randomized controlled trial; OO, olive oil; P, processed meat; PLS, partial least squares; pro, protein food component; PUFA, polyunsaturated fatty acids; PUFA:SFA, polyunsaturated fatty acid-to-saturated fatty acid ratio; R, red meat; RCT, randomized controlled trial; RRR, reduced rank regression; S, seafood; Se, seeds; SFA, saturated fatty acids; SSB, sugar-sweetened beverage; UFA, unsaturated fatty acid; Vit, vitamin; w/, with; W, white meat; W:R, white-to-red meat ratio; Wi, wine