# Appendix 4 Literature search strategy

## Search from existing review

The search conducted for an existing review identified articles published between January 1980 and January 2017. For the complete search documentation, refer to:

Raghavan R, Dreibelbis C, Kingshipp BJ, . Dietary Patterns before and during Pregnancy and Gestational Age- and Sex-Specific Birth Weight: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0104 .

## Search for the current review

This search was first run on June 8, 2022, and then periodically run using NESR’s continuous evidence monitoring methods^*^.

* USDA Nutrition Evidence Systematic Review Branch. Chapter 10: Continuous Evidence Monitoring. In: USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview.

[underlined: Database: PubMed]

Provider: U.S. National Library of Medicine

Date(s) Searched: June 8, 2022 (initial search); June 8, 2022 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 6, 2017 – January 9, 2024

Table A 4 Search for PubMed

Search # | Concept | String
#1 | Birth weight and gestational age | “Birth Weight”[Mesh] OR “Infant, Low Birth Weight”[Mesh] OR “Gestational Age”[Mesh] OR birthweight[tiab] OR ((fetal[tiab] OR “foetal”[tiab] OR baby[tiab] OR babies[tiab] OR infant*[tiab] OR birth[tiab] OR births[tiab] OR newborn[tiab]) AND (weight*[tiab])) OR “Gestational Age”[tiab] OR “Obstetric Labor, Premature”[Mesh] OR ((prematur*[tiab] OR pre-matur*[tiab] OR preterm[tiab] OR pre-term[tiab] OR “before term”[tiab]) AND (baby[tiab] OR infant*[tiab] OR birth[tiab] OR labor[tiab] OR membrane*[tiab] OR babies[tiab])) OR “Fetal Growth Retardation”[Mesh] OR IUGR[tiab] OR “Fetal Development”[Mesh:NoExp] OR “Fetal Weight”[Mesh] OR fetal development[tiab] OR “foetal development”[tiab] OR ((fetal[tiab] OR “foetal”[tiab] OR intrauterine[tiab] OR intra-uterine[tiab]) AND (growth[tiab]))
#2 | Dietary patterns | (“dietary pattern*”[tiab] OR “diet pattern*”[tiab] OR “eating pattern*”[tiab] OR “food pattern*”[tiab] OR “diet quality”[tiab] OR “dietary quality”[tiab] OR “diet variety”[tiab] OR “dietary variety”[tiab] OR “varied diet”[tiab] OR “dietary guideline*”[tiab] OR “dietary recommendation*”[tiab] OR “dietary intake*”[tiab] OR “eating style*”[tiab] OR “Diet, Mediterranean”[Mesh] OR “Mediterranean Diet*”[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR “Dietary Approaches To Stop Hypertension Diet*”[tiab] OR “DASH diet*”[tiab] OR “Diet, Gluten-Free”[Mesh] OR “Gluten Free diet*”[tiab] OR “prudent diet*”[tiab] OR “Diet, Paleolithic”[Mesh] OR “Paleolithic Diet*”[tiab] OR “Diet, Vegetarian”[Mesh] OR “vegetarian diet*”[tiab] OR “vegan diet*”[tiab] OR “Diet, Healthy”[Mesh] OR “healthy diet*”[tiab] OR “plant based diet*”[tiab] OR “Diet, Western”[Mesh] OR “western diet*”[tiab] OR “Nordic Diet*”[tiab] OR “Okinawan diet*”[tiab] OR “Diet, Fat-Restricted”[Mesh] OR “Diet, HighFat”[Mesh] OR “high-fat diet*”[tiab] OR “low fat diet*”[tiab] OR “Diet, Sodium- Restricted”[Mesh] OR “low-sodium diet*”[tiab] OR “low salt diet*”[tiab] OR ((“Guideline Adherence”[Mesh] OR “guideline adherence*”[tiab])AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage*[tiab] OR nutrition*[tiab])) OR “diet score*”[tiab] OR “diet quality score*”[tiab] OR “diet quality index*”[tiab] OR kidmed[tiab] OR “diet index*”[tiab] OR “dietary index*”[tiab] OR “food score*”[tiab] OR MedDietScore[tiab] OR “healthy eating index”[tiab])
#3 | Pre-pregnancy and pregnancy | Pregnancy[Mesh] OR “Pregnancy Complications”[Mesh] OR “Maternal Exposure”[Mesh] OR “Pregnant Women”[Mesh] OR “Prenatal Exposure Delayed Effects”[Mesh] OR “Peripartum Period”[Mesh] OR “Maternal Nutritional Physiological Phenomena”[Mesh] OR pregnan*[tiab] OR prepregnancy[tiab] OR prenatal[tiab] OR perinatal[tiab] OR pre-conception[tiab] OR preconception[tiab] OR peri-conception[tiab] OR periconception[tiab] OR peripartum[tiab] OR peri-partum[tiab] OR gestation*[tiab] OR natal[tiab] OR antenatal[tiab]
#4 | | #1 AND #2 AND #3
#5 | Limits | #4 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); from 2017/1/6 - 3000/12/12

[underlined: Database: Embase]

Provider: Elsevier

Date(s) Searched: June 8, 2022 (initial search); June 8, 2022 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 6, 2017 – January 9, 2024

Table A 5 Search for Embase

Search # | Concept | String
#1 | Birth weight and gestational age | ‘Birth Weight’/exp OR ‘Gestational Age’/exp OR ‘large for gestational age’/exp OR ‘premature labor’/exp OR ‘intrauterine growth retardation’/exp OR ‘prenatal development’/de OR ‘fetus development’/de OR ‘fetus weight’/exp OR birthweight:ab,ti OR ‘gestational age’:ab,ti OR IUGR:ab,ti OR ‘fetal development’:ab,ti OR ‘foetal development’:ab,ti OR ((fetal OR foetal OR baby OR babies OR infant* OR birth OR births OR newborn) NEAR/6 weight*):ab,ti OR ((prematur* OR pre-matur* OR preterm OR ‘pre term’ OR ‘before term’) NEAR/6 (baby OR babies OR infant* OR birth OR labor OR membrane*)):ab,ti OR ((fetal OR foetal OR intrauterine OR ‘intra uterine’) NEAR/6 growth):ab,ti
#2 | Dietary patterns | ‘feeding behavior’/de OR ‘mediterranean diet’/exp OR ‘dash diet’/exp OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/exp OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein restriction’/exp OR ‘sodium restriction’/exp OR ‘nordic diet’/de OR ‘protein diet’/exp OR ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality’:ab,ti OR ‘dietary quality’:ab,ti OR ‘diet variety’:ab,ti OR ‘dietary variety’:ab,ti OR ‘varied diet’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake*’:ab,ti OR ‘eating style*’:ab,ti OR ‘Mediterranean Diet*’:ab,ti OR ‘Dietary Approaches To Stop Hypertension Diet*’:ab,ti OR ‘DASH diet*’:ab,ti OR ‘Gluten Free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘Paleolithic Diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘healthy diet*’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘Nordic Diet*’:ab,ti OR ‘Okinawan Diet*’:ab,ti OR ‘high-fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti OR ‘diet score*’:ab,ti OR ‘diet quality score*’:ab,ti OR ‘diet quality index*’:ab,ti OR kidmed:ab,ti OR ‘diet index*’:ab,ti OR ‘dietary index*’:ab,ti OR ‘food score*’:ab,ti OR MedDietScore:ab,ti OR ‘healthy eating index’:ab,ti OR (‘guideline adherence*’ AND (diet OR dietary OR food OR beverage* OR nutrition*)):ab,ti
#3 | Pre-pregnancy and pregnancy | ‘Pregnancy’/exp OR ‘Pregnancy Complications’/exp OR ‘Maternal Exposure’/exp OR ‘Pregnant Woman’/exp OR ‘Prenatal exposure’/exp OR ‘perinatal exposure’/exp OR ‘Perinatal Period’/exp OR ‘maternal nutrition’/exp OR pregnan*:ab,ti OR prepregnancy:ab,ti OR prenatal:ab,ti OR perinatal:ab,ti OR ‘pre-conception’:ab,ti OR preconception:ab,ti OR ‘peri-conception’:ab,ti OR periconception:ab,ti OR peripartum:ab,ti OR ‘peri-partum’:ab,ti OR gestation*:ab,ti OR natal:ab,ti OR antenatal:ab,ti
#4 | | #1 AND #2 AND #3
#5 | Limits | #4 AND ([article]/lim OR [article in press]/lim) NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)) AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’:ab,ti OR ‘retraction notice’:ti OR ‘retracted publication’:ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR ‘practice guideline’:ti) AND [2017–2024]/py

[underlined: Database: Cochrane Central Register of Controlled Trials (CENTRAL)]

Provider: John Wiley & Sons

Date(s) Searched: June 8, 2022 (initial search); June 8, 2022 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 6, 2017 – January 9, 2024

Table A 6 Search for Cochrane CENTRAL

Search # | Concept | String
#1 | Birth weight and gestational age | [mh “Birth Weight”] OR [mh “Infant, Low Birth Weight”] OR [mh “Gestational Age”] OR [mh “Obstetric Labor, Premature”] OR [mh “Fetal Growth Retardation”] OR [mh ^“Fetal Development”] OR [mh “Fetal Weight”] OR (birthweight OR “gestational age” OR IUGR OR “fetal development” OR “foetal development” OR ((fetal OR foetal OR baby OR babies OR infant* OR birth OR births OR newborn) NEAR/6 weight*) OR ((prematur* OR pre-matur* OR preterm OR “pre term” OR “before term”) NEAR/6 (baby OR babies OR infant* OR birth OR labor OR membrane*)) OR ((fetal OR foetal OR intrauterine OR “intra uterine”) NEAR/6 growth)):ti,ab,kw
#2 | Dietary patterns | [mh “Diet, Mediterranean”] OR [mh “Dietary Approaches To Stop Hypertension”] OR [mh “Diet, Gluten-Free”] OR [mh “Diet, Paleolithic”] OR [mh “Diet, Vegetarian”] OR [mh “Diet, Healthy”] OR [mh “Diet, Western”] OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, Sodium-Restricted”] OR [mh “Guideline Adherence”] OR (“dietary pattern” OR “dietary patterns” OR “diet pattern” OR “diet patterns” OR “eating pattern” OR “eating patterns” OR “food pattern” OR “food patterns” OR “diet quality” OR “dietary quality” OR “diet variety” OR “dietary variety” OR “varied diet” OR “dietary guideline” OR “dietary guidelines” OR “dietary recommendation” OR “dietary recommendations” OR “dietary intake” OR “dietary intakes” OR “eating style” OR “eating styles” OR “Mediterranean Diet” OR “Mediterranean Diets” OR “Dietary Approaches To Stop Hypertension Diet” OR “Dietary Approaches To Stop Hypertension Diets” OR “DASH diet” OR “DASH diets” OR “Gluten Free diet” OR “Gluten Free diets” OR “prudent diet” OR “prudent diets” OR “Paleolithic Diet” OR “Paleolithic Diets” OR “vegetarian diet” OR “vegetarian diets” OR “vegan diet” OR “vegan diets” OR “healthy diet” OR “healthy diets” OR “plant based diet” OR “plant based diets” OR “Western diet” OR “Western diets” OR “Nordic Diet” OR “Nordic Diets” OR “Okinawan Diet” OR “Okinawan Diets” OR “high-fat diet” OR “high-fat diets” OR “low fat diet” OR “low fat diets” OR “low-sodium diet” OR “low-sodium diets” OR “low salt diet” OR “low salt diets” OR “diet score” OR “diet scores” OR “diet quality score” OR “diet quality scores” OR “diet quality index” OR “diet quality indexes” OR “diet quality indices” OR kidmed OR “diet index” OR “diet indexes” OR “diet indices” OR “dietary index” OR “dietary indexes” OR “dietary indices” OR “food score” OR “food scores” OR MedDietScore OR “healthy eating index” OR “healthy eating indexes” OR “healthy eating indices”):ti,ab,kw OR (“guideline adherence” NEAR/2 (diet OR dietary OR food OR beverage* OR nutrition*)):ti,ab,kw
#3 | Pre-pregnancy and pregnancy | [mh Pregnancy] OR [mh “Pregnancy Complications”] OR [mh “Maternal Exposure”] OR [mh “Pregnant Women”] OR [mh “Peripartum Period”] OR [mh “Prenatal Exposure Delayed Effects”] OR [mh “Peripartum Period”] OR [mh “Maternal Nutritional Physiological Phenomena”] OR (pregnan* OR prepregnancy OR prenatal OR perinatal OR “pre-conception” OR preconception OR “peri-conception” OR periconception OR peripartum OR “peri-partum” OR gestation* OR natal OR antenatal):ti,ab,kw
#4 | | #1 AND #2 AND #3; In trials, word variations searched; Custom publication range: 2017 - 2024

[underlined: Database: CINAHL]

Provider: EBSCO

Date(s) Searched: June 8, 2022 (initial search); June 8, 2022 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 6, 2017 – January 9, 2024

Table A 7 Search for CINAHL

Search # | Concept | String
#1 | Birth weight and gestational age | (MH “Birth Weight”) OR (MH “Infant, Low Birth Weight+”) OR (MH “Infant, Large for Gestational Age”) OR (MH “Gestational Age”) OR (MH “Labor, Premature”) OR (MH “Fetal Growth Retardation”) OR (MH “Fetal Weight”) OR (MH “Fetal Development”) OR (TI birthweight OR “gestational age” OR IUGR OR “fetal development” OR “foetal development” OR ((fetal OR foetal OR baby OR babies OR infant* OR birth OR births OR newborn) N6 weight*) OR ((prematur* OR pre-matur* OR preterm OR “pre term” OR “before term”) N6 (baby OR babies OR infant* OR birth OR labor OR membrane*)) OR ((fetal OR foetal OR intrauterine OR “intra uterine”) N6 growth)) OR (AB birthweight OR “gestational age” OR IUGR OR “fetal development” OR “foetal development” OR ((fetal OR foetal OR baby OR babies OR infant* OR birth OR newborn) N6 weight*) OR ((prematur* OR preterm OR “pre term” OR “before term”) N6 (baby OR babies OR infant* OR birth OR labor OR membrane*)) OR ((fetal OR foetal OR intrauterine OR “intra uterine”) N6 growth))
#2 | Dietary patterns | (MH “Mediterranean Diet”) OR (MH “DASH Diet”) OR (MH “Diet, Gluten-Free”) OR (MH “Diet, Paleolithic”) OR (MH “Vegetarianism”) OR (MH “Diet, Western”) OR (MH “Diet, Fat-Restricted”) OR (MH “Diet, Sodium-Restricted”) OR (MH “Restricted Diet”) OR (MH “Diet, High Protein”) OR (MH “Diet, Nordic”) OR (MH “Plant-Based Diet”) OR (TI “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “diet variety” OR “dietary variety” OR “varied diet” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR “Mediterranean Diet*” OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR “Gluten Free diet*” OR “prudent diet*” OR “Paleolithic Diet*” OR “Okinawan diet” OR “vegetarian diet*” OR “vegan diet*” OR “healthy diet*” OR “plant based diet*” OR “western diet*” OR “Nordic Diet*” OR “high-fat diet*” OR “low fat diet*” OR “low-sodium diet*” OR “low salt diet*” OR “diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index”) OR (AB “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “diet variety” OR “dietary variety” OR “varied diet” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR “Mediterranean Diet*” OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR “Gluten Free diet*” OR “prudent diet*” OR “Paleolithic Diet*” OR “Okinawan diet” OR “vegetarian diet*” OR “vegan diet*” OR “healthy diet*” OR “plant based diet*” OR “western diet*” OR “Nordic Diet*” OR “high-fat diet*” OR “low fat diet*” OR “low-sodium diet*” OR “low salt diet*” OR “diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index”) OR ((MH “Guideline Adherence”) OR (TI “guideline adherence*”) OR (AB “guideline adherence*”)) AND ((TI diet OR dietary OR food OR beverage* OR nutrition*) OR (AB diet OR dietary OR food OR beverage* OR nutrition*))
#3 | Pre-pregnancy and pregnancy | (MH “Pregnancy+”) OR (MH “Pregnancy Complications+”) OR (MH “Maternal Exposure”) OR (MH “Expectant Mothers”) OR (MH “Prenatal Exposure Delayed Effects”) OR (MH “Maternal Nutritional Physiology+”) OR (TI pregnan* OR prepregnancy OR prenatal OR perinatal OR “pre-conception” OR preconception OR “peri-conception” OR periconception OR peripartum OR “peri-partum” OR gestation* OR natal OR antenatal) OR (AB pregnan* OR prepregnancy OR prenatal OR perinatal OR “pre-conception” OR preconception OR “peri-conception” OR periconception OR peripartum OR “peri-partum” OR gestation* OR natal OR antenatal)
#4 | | #1 AND #2 AND #3
#5 | | #4 NOT ((MH “Animals+”) OR (MH “Animal Studies”)) NOT ((MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication) OR (MH “Congresses and Conferences”)); English, Apply equivalent subjects; Published Date: 20170101–20240109