# Appendix 2 Conclusion statements from the existing systematic review

Table A 2 Conclusion statements from the existing systematic review for the research question: What is the relationship between dietary patterns consumed during pregnancy and birth weight?

Citation | Conclusion statements and grades
Raghavan R, Dreibelbis C, Kingshipp BJ, Wong, YP, Terry N, Abrams B, Bartholomew A, Bodnar LM, Gernand A, Rasmussen K, Siega-Riz AM, Stang JS, Casavale KO, Spahn JM, Stoody E. Dietary Patterns before and during Pregnancy and Gestational Age- and Sex-Specific Birth Weight: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0104. | - No conclusion can be drawn on the association between dietary patterns during pregnancy and birth weight outcomes. Although research is available, the ability to draw a conclusion is restricted by; - inconsistency in study findings,; - inadequate adjustment of birth weight for gestational age and sex, and; - variation in study design, dietary assessment methodology, and adjustment of key confounding factors.; - Insufficient evidence exists to estimate the association between dietary patterns before pregnancy and birth weight outcomes. There are not enough studies available to answer this question.