# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body mass index
EVOO: Extra virgin olive oil
GDM: Gestational diabetes mellitus
HDP: Hypertensive disorders of pregnancy
HEI: Healthy Eating Index
HHS: United States Department of Health and Human Services
LBW: Low birth weight
LGA: Large-for-gestational age
NESR: Nutrition Evidence Systematic Review
NICHD: Eunice Kennedy Shriver National Institutes of Child Human Development
NRCT: Non-randomized controlled trial
PCS: Prospective cohort study
RCT: Randomized controlled trial
SEP: Socioeconomic position
SGA: Small-for-gestational age
SSB: Sugar-sweetened beverage
USDA: United States Department of Agriculture