# References of the articles included in the systematic review

1 Alves-Santos N, Cocate PG, Cocate P, Prepregnancy Dietary Patterns and Their Association with Perinatal Outcomes: A Prospective Cohort Study. J Acad Nutr Diet. 2019;119(9):1439–1451.31053516
2 Bodnar LM, Kirkpatrick SI, Parisi SM, Jin Q, Naimi AI. Periconceptional Dietary Patterns and Adverse Pregnancy and Birth Outcomes. J Nutr. 2024;154:680–690.38122847
3 Chia A-R, de Seymour JV, Colega M, A vegetable, fruit, and white rice dietary pattern during pregnancy is associated with a lower risk of preterm birth and larger birth size in a multiethnic Asian cohort: the Growing Up in Singapore Towards healthy Outcomes (GUSTO) cohort study. Am J Clin Nutr. 2016;104(5):1416–1423. doi:10.3945/ajcn.116.133892 27733407
4 Chia AR, Tint MT, Han CY, Adherence to a healthy eating index for pregnant women is associated with lower neonatal adiposity in a multiethnic Asian cohort: the Growing Up in Singapore Towards healthy Outcomes (GUSTO) Study. Am J Clin Nutr. 2018;107:71–79.29381790
5 de Seymour JV, Beck KL, Conlon CA, An Investigation of the Relationship Between Dietary Patterns in Early Pregnancy and Maternal/Infant Health Outcomes in a Chinese Cohort. Front Nutr. 2022;9:775557. doi:10.3389/fnut.2022.775557 35529458
6 Englund-Ögge L, AL. B, V S, Maternal dietary patterns and preterm delivery: results from large prospective cohort study. BMJ. 2014;348:g1446. doi:10.1136/bmj.g1446 24609054
7 Fulay AP, Rifas-Shiman SL, Oken E, Perng W. Associations of the dietary approaches to stop hypertension (DASH) diet with pregnancy complications in Project Viva. Eur J Clin Nutr. 2018;72(10):1385–1395. doi:10.1038/s41430-017-0068-8 29339829
8 Grieger JA, Grzeskowiak LE, Clifton VL. Preconception dietary patterns in human pregnancies are associated with preterm delivery. J Nutr. 2014;144(7):1075–80. doi:10.3945/jn.114.190686 24790026
9 Haugen M, Meltzer H.M. Brantsaeter AL, T. M, Mediterranean-type diet and risk of preterm birth among women in the Norwegian Mother and Child Cohort Study (MoBa): a prospective cohort study. Acta Obstet Gynecol, Scand. 2008;87(3):319–324. doi:10.1080/00016340801899123.18307072
10 Hillesund ER, Bere E, Sagedal LR, Pre-pregnancy and early pregnancy dietary behavior in relation to maternal and newborn health in the Norwegian Fit for Delivery study - a post hoc observational analysis. Food Nutr Res. 2018;62(1654-661X (Print))doi:10.29219/fnr.v62.1273
11 Hillesund ER, C. ØN, Engel SM, Associations of adherence to the New Nordic Diet with risk of preeclampsia and preterm delivery in the Norwegian Mother and Child Cohort Study (MoBa). Eur J Epidemiol. 2014;29(10):753–65. doi:10.1007/s10654-014-9948-6 25193741
12 Hu J, Li M, Li C, Trimester-specific associations of maternal dietary patterns with preterm birth: China Medical University birth cohort study. Food Func. 2023;14(16):7682–7691. doi:10.1039/d3fo00691c
13 Lecorguillé M, Lioret S, de Lauzon-Guillain B, Association between Dietary Intake of One-Carbon Metabolism Nutrients in the Year before Pregnancy and Birth Anthropometry. Nutrients. 2020;12(3):838. doi:10.3390/nu12030838 32245126
14 Li M, Grewal J, Hinkle SN, Healthy dietary patterns and common pregnancy complications: a prospective and longitudinal study. Am J Clin Nutr. 2021;114(3):1229–1237. doi:10.1093/ajcn/nqab145 34075392
15 Lu MS, He JR, Chen Q, Maternal dietary patterns during pregnancy and preterm delivery: a large prospective cohort study in China. Nutr J. 2018;17:71. doi:10.1186/s12937-018-0377-3 30045719
16 Makarem N, Chau K, Miller EC, Association of a Mediterranean Diet Pattern With Adverse Pregnancy Outcomes Among US Women. JAMA Netw Open. 2022;5(12):e2248165. doi:10.1001/jamanetworkopen.2022.48165 36547978
17 Maldonado L, Farzan SF, Toledo-Corral CM, A Vegetable, Oil, and Fruit Dietary Pattern in Late Pregnancy is Linked to Reduced Risks of Adverse Birth Outcomes in a Predominantly Low-Income Hispanic and Latina Pregnancy Cohort. J Nutr. 2022;152(12):2837–2846. doi:10.1093/jn/nxac209
18 Martin CL, Sotres-Alvarez D, Siega-Riz AM. Maternal Dietary Patterns during the Second Trimester Are Associated with Preterm Birth. J Nutr. 2015;145(8):1857–64. doi:10.3945/jn.115.212019 26084362
19 Miele M, Souza R, Calderon IM, Maternal Nutrition Status Associated with Pregnancy-Related Adverse Outcomes. Nutrients. 2021;13(7):2398. doi:10.3390/nu13072398 34371906
20 Mikkelsen TB, M.L. O, Knudsen VK, Association between a Mediterranean-type diet and risk of preterm birth among Danish women: a prospective cohort study. Acta Obstet Gynecol Scand. 2008;87(3):325–30. doi:10.1080/00016340801899347 18307073
21 Mitku A, Zewotir T, North D, Jeena P, Naidoo R. Modeling Differential Effects of Maternal Dietary Patterns across Severity Levels of Preterm Birth Using a Partial Proportional Odds Model. Sci Rep. 2020;10(1):5494. doi:10.1038/s41598-020-62447-4 32218502
22 Navarro P, Mehegan J, Murrin CA-O, Kelleher CC, Phillips CM. Associations between a maternal healthy lifestyle score and adverse offspring birth outcomes and childhood obesity in the Lifeways Cross-Generation Cohort Study. Nutrients. 2019;11(4):928. doi:10.3390/nu11040928 31027168
23 Paknahad ZA-O, Fallah A, Moravejolahkami AR. Maternal Dietary Patterns and Their Association with Pregnancy Outcomes. Clin Nutr Res. 2019;8(1):64–73. doi:10.7762/cnr.2019.8.1.64 30746349
24 Parisi F, Savasi VM, di Bartolo I, Mandia L, Cetin IA-O. Associations between First Trimester Maternal Nutritional Score, Early Markers of Placental Function, and Pregnancy Outcome. Nutrients. 2020;12(6)doi:10.3390/nu12061799
25 Rasmussen MA, Maslova E, Halldorsson TI, Olsen SF. Characterization of dietary patterns in the Danish national birth cohort in relation to preterm birth. PLoS ONE. 2014;9(4):e93644. doi:10.1371/journal.pone.0093644 24747715
26 Robinson DT, Van Horn L, Balmert L, Dietary Fat and Fatty Acid Intake in Nulliparous Women: Associations with Preterm Birth and Distinctions by Maternal BMI. Curr Dev Nutr. 2021;5(6)doi:10.1093/cdn/nzab074
27 Wang Z, Zhao S, Cui X, Effects of Dietary Patterns during Pregnancy on Preterm Birth: A Birth Cohort Study in Shanghai. Nutrients. 2021;13(7):2367. doi:10.3390/nu13072367 34371874
28 Yee LM, Silver RM, Haas DM, Quality of periconceptional dietary intake and maternal and neonatal outcomes. Am J Obstet Gynecol. 2020;223(1):121. doi:10.1016/j.ajog.2020.01.042
29 Yisahak S, Mumford SL, Grewal J, Maternal diet patterns during early pregnancy in relation to neonatal outcomes. Am J Clin Nutr. 2021;114(1):358–367.33742192
30 Zhu Y, Hedderson MM, Brown SD, Healthy preconception and early-pregnancy lifestyle and risk of preterm birth: a prospective cohort study. Am J Clin Nutr. 2021;114(2):813–821. doi:10.1093/ajcn/nqab089 33900396
31 Al Wattar BH, Dodds J, Placzek A, Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): A pragmatic multicentre randomised trial. PLoS Med. 2019;16(7):e1002857. doi:10.1371/journal.pmed.1002857 31335871
32 Assaf-Balut C, García de la Torre N, Durán A, A Mediterranean diet with additional extra virgin olive oil and pistachios reduces the incidence of gestational diabetes mellitus (GDM): A randomized controlled trial: The St. Carlos GDM prevention study. PLoS One. 2017;12(10):e0185873. doi:10.1371/journal.pone.0185873 29049303
33 Assaf-Balut C, García de la Torre N, Duran A, A Mediterranean Diet with an Enhanced Consumption of Extra Virgin Olive Oil and Pistachios Improves Pregnancy Outcomes in Women Without Gestational Diabetes Mellitus: A Sub-Analysis of the St. Carlos Gestational Diabetes Mellitus Prevention Study. Ann Nutr Metab. 2019;74(1):69–79. doi:10.1159/000495793 30554220
34 Crovetto F, Crispi F, Casas R, Effects of Mediterranean Diet or Mindfulness-Based Stress Reduction on Prevention of Small-for-Gestational Age Birth Weights in Newborns Born to At-Risk Pregnant Individuals: The IMPACT BCN Randomized Clinical Trial. JAMA. 2021;326(21):2150–2160.34874420
35 Dodd J, Deussen A, Louise J. A Randomised Trial to Optimise Gestational Weight Gain and Improve Maternal and Infant Health Outcomes through Antenatal Dietary, Lifestyle and Exercise Advice: The OPTIMISE Randomised Trial. Nutrients. 2019;11(12):2911. doi:10.3390/nu11122911 31810217
36 Gallagher D, Rosenn B, Toro-Ramos T, Greater Neonatal Fat-Free Mass and Similar Fat Mass Following a Randomized Trial to Control Excess Gestational Weight Gain. Obesity. 2018;26(3):578–587. doi:10.1002/oby.22079 29464905
37 Khoury J, Henriksen TC, B. Tonstad, S. Effect of a cholesterol-lowering diet on maternal, cord, and neonatal lipids, and pregnancy outcome: a randomized clinical trial. Am J Obstet Gynecol. 2005;193(4):1292–301. doi:10.1016/j.ajog.2005.05.016 16202717
38 Melero V, García de la Torre N, Assaf-Balut C, Effect of a Mediterranean Diet-Based Nutritional Intervention on the Risk of Developing Gestational Diabetes Mellitus and Other Maternal-Fetal Adverse Events in Hispanic Women Residents in Spain. Nutrients. 2020;12(11):3505. doi:10.3390/nu12113505 33202607
39 Van Horn L, Peaceman A, Kwasny M, Dietary Approaches to Stop Hypertension Diet and Activity to Limit Gestational Weight: Maternal Offspring Metabolics Family Intervention Trial, a Technology Enhanced Randomized Trial. Am J Prev Med. 2018;55(5):603–614. doi:10.1016/j.amepre.2018.06.015 30262148
40 Zhao L, Zhang P, Zheng Q, Deka A, Choudhury R, Rastogi S. Does a MediDiet With Additional Extra Virgin Olive Oil and Pistachios Reduce the Incidence of Gestational Diabetes? Endocr Pract. 2022;28(2):135–141. doi:10.1016/j.eprac.2021.08.010 34481972