# Summary of conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee answered the systematic review question: “What is the relationship between dietary patterns consumed during pregnancy and gestational age at birth?” with the following conclusion statement.^*^ The grade reflects the strength of the evidence underlying the conclusion statement.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

Dietary patterns consumed during pregnancy may not be associated with risk of preterm birth. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

## Research recommendations

To more adequately assess the relationship between dietary patterns during pregnancy and risk of preterm birth, additional research is needed that should:

1. Include populations representative of all Americans, such as diversity in race and/or ethnicity, socioeconomic position, disability status, and gender identity. Of note, no included studies reported including American Indian or Alaska Native participants.
2. Clearly describe characteristics related to health disparities (e.g., racial or ethnic group, religion, socioeconomic status, gender, age, or mental health; cognitive, sensory, or physical disability; sexual orientation or gender identity; geographic location; substance use; or other characteristics historically linked to discrimination or exclusion).
3. Conduct well-designed and sufficiently powered trials where the isolated effect of the dietary pattern on the outcome can be determined and where the dietary patterns and comparator patterns are fully described. Include details pertaining to the food groups to enhance ability to make comparisons with other studies.
4. Consider stratifying analyses by race and/or ethnicity or socioeconomic position (or other social determinants of health) or account for these and other key confounders in methods and/or analyses.
5. Consider the type of preterm birth (i.e., spontaneous vs. medically-indicated) in the study design and/or analytic plan.
6. Include strong justification when controlling for variables that occur after the start of the exposure period (i.e., pregnancy) that could have been affected by the exposure, such as gestational weight gain.
7. Administer dietary assessments as early as possible in and multiple times throughout pregnancy, use validated and reliable assessment methods, such as multiple 24 hour recalls and food frequency questionnaires validated for the population, and provide clear information on the period of time captured by the assessments.
8. In addition to other planned analyses, evaluate the dietary pattern against existing indices of dietary quality (e.g., HEI) to facilitate comparison across studies.
9. Collect information on prenatal supplementation and consider supplementation in study design and/or analytic plan.

Table 7 Evidence examining the relationship between dietary patterns consumed during pregnancy and risk of preterm birth^a^

Study Characteristics | Intervention or Exposure and Outcome | Results | Confounders, Funding, and Summary
RCT
Al Wattar, 2019^31^; RCT, Parallel-arm, U. K., ESTEEM; Baseline N=1,252; Analytic N= 1,137 (Attrition: 9%); - Age (y): IG: 31.4±5.2; CG: 30.9±5.2; ○ >40 (%): IG: 3.9; CG: 3.1; - Race/Ethnicity (%):; White: IG: 36.6; CG: 35.5;; Asian: IG: 43.4; CG: 44.1;; Black: IG: 16.4; CG: 17.2;; Other: IG: 3.7; CG: 3.3; - Baseline BMI (%): 25-29.9: IG: 16.7; CG: 16.7; ≥30: IG: 69.1; CG: 69.6; - Current HDP (%): PE: IG: 6.2; CG: 4.6; - Current DM (%): GDM: IG: 17.6; CG: 24.9, p=0.01 | IG vs CG; 24 HR at baseline (~18 GW);; ESTEEM Q at 20, 24, 28, 32, and 36 GW; DP Description:; - Control (CG): Received usual care and antenatal dietary advice as per U.K. national recommendations; - Intervention (IG): High intake of nuts, extra virgin olive oil, fruit, vegetables, nonrefined grains, and legumes; moderate to high consumption of fish; low to moderate intake of poultry and dairy products; low consumption of red meat and processed meat; and avoidance of sugary drinks, fast food, and food rich in animal fat. Participants provided with 30 g/d of mixed nuts and 0.5 L/wk of EVOO.; Adherence: ESTEEM Q score did not differ between groups at baseline but was significantly higher in IG vs CG after the intervention.; - Positive components: Olive oil (as main fat and svg/d); Nuts (including peanuts) Vegetables; Fruit (including juice); Pulses; Fish or shellfish; White meat over red meat; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial sweets or pastries; Outcomes:; PTB: <37 GW, <34 GW | PTB <37 GW; Multivariable logistic regression; aOR (95% CI); 0.82 (0.55, 1.22), p=0.33; PTB <34 GW; Multivariable logistic regression; aOR (95% CI); 0.92 (0.51, 1.67), p=0.79 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI, Current HDP; Other covariates: Personal history of GDM; Family history of hypertensive disorders; Family history of DM; Personal history of stillbirth; Recruitment center; Funding: Barts Charity; California Walnut Commission and Blue Diamond Growers donated walnuts and almonds, respectively; Summary: A simple, individualized, Mediterranean-style DP supplemented with mixed nuts and EVOO did not have an effect on risk of PTB <37 GW or <34 GW compared to usual care.
Assaf-Balut, 2017^32^; RCT, Parallel-arm, Spain, The St. Carlos GDM Prevention Study; Analytic N=874 (Attrition: 13%); - Age (y): CG: 32.7±5.3; IG: 33.2±5.0; - Race/Ethnicity (%): White: CG: 67.8; IG: 69.0; Hispanic: CG: 28.4; IG: 28.6; Other: CG: 3.8; IG: 2.4; - Socioeconomic position:; ○ Education (%): Elementary:; CG: 10.8; IG: 6.8; University:; CG: 50.2; IG: 50.4; ○ Employment (%): CG: 75.2; IG: 78.0; - Pre-pregnancy BMI: CG: 23.3±4.0; IG: 22.9±3.6; - Current HDP (%):; ○ Gestational HTN: CG: 4.3; IG: 3.0; ○ PE: CG: 2.5; IG: 1.6; - Current DM (%): GDM: CG: 23.4; IG: 17.1, p=0.012; - Smoking (%): CG: 8.0; IG: 8.6 | IG vs CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - Both the intervention group (IG) and control group (CG) given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg/wk legumes, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals. They were also instructed to be physically active and walk >30 min/d.; - IG recommended to consume ≥40 mL/d of EVOO and a handful (25-30 g/d) of pistachios and were provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ between groups at baseline. Scores significantly increased over time in both groups, but scores remaining significantly higher in the IG compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries; Outcomes:; PTB: <37 GW, <34 GW | PTB <37 GW; Logistic regression; RR (95% CI); 0.30 (0.11, 0.79), p=0.016; PTB <34 GW; Chi-squared test, %; CG: 0.9; IG: 0.0, p=NR | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI, Current HDP; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Fondo Europeo de Desarrollo Regiona; Summary: A MedDiet supplemented with EVOO and pistachios reduced risk of PTB <37 GW compared to lower alignment with a MedDiet.
Assaf-Balut, 2019^33^; RCT, Spain, The St. Carlos GDM Prevention Study; Analytic N=697 (Attrition: 15%); - Age (y): CG: 32.54±5.29; IG: 32.92±4.92; - Race/Ethnicity (%): White: CG: 67.1; IG: 67.8; Hispanic: CG: 29.1; IG: 30.3; Other: CG: 3.9; IG: 1.9; - Socioeconomic position: Education (%): Elementary: CG: 7.6; IG: 6.1; University: CG: 50.1; IG: 51.4 Employment (%): CG: 75.3; IG: 79.2; - Pre-pregnancy BMI: CG: 22.9±3.8; IG: 22.4±3.3; - Current HDP (%): Gestational HTN: CG: 3.3; IG: 3.6 PE: CG: 1.2; IG: 1.9; - Current DM (%): GDM: 0.0; - Smoking (%): CG: 7.4; IG: 8.3 | IG vs CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - Both the intervention group (IG) and control group (CG) given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg/wk legumes, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals. They were also instructed to be physically active and walk >30 min/d.; - IG recommended to consume ≥40 mL/d of EVOO and a handful (25-30 g/d) of pistachios and were provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ at baseline. Scores significantly increased over time in both groups, but scores remained significantly higher in the IG compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries; Outcomes:; PTB <37 GW | PTB <37 GW; Logistic regression; RR (95% CI); 0.33 (0.11, 1.06), p=0.067 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Among normoglycemic participants, the effect of a MedDiet supplemented with EVOO and pistachios neared statistical significance for reduced risk of PTB <37 GW compared to lower alignment with a MedDiet.
Crovetto, 2021^34^; RCT, Parallel-arm, Spain, IMPACT BCN; Baseline N=814; Analytic N=793 (Attrition: 3%); - Age (y): Median (IQR): IG: 37.2 (34.5-40.4); CG: 37 (33.2-40.5); - Race/Ethnicity (%): White: IG: 80.1; CG: 78.8; Latin American: IG: 13.8; CG: 15.2; Maghreb: IG: 2.0; CG: 2.2; Asian: IG: 2.0; CG: 2.0; Black: IG: 2.0; CG: 1.7; - Socioeconomic position:; ○ SES (%): High: IG: 59.7; CG: 57.1; Low: IG: 5.1; CG: 7.2; - Pre-pregnancy BMI: IG: 24±4.8; CG: 23.9±4.8; - Current HDP (%):; ○ Gestational HTN: IG: 2.0; CG: 2.3; ○ PE: IG: 5.6; CG: 9.3, p=0.05; ○ Eclampsia: IG: 0.3; CG: 0.0; - Current DM (%):; ○ DM: IG: 5.4; CG: 4.0; ○ GDM: IG: 12.2; CG: 7.5, p=0.03; - Smoking (%): IG: 6.9; CG: 9.5 | IG vs CG; FFQ and 7d diet journal at: 19-23.6 GW and 34-36 GW; DP Description:; - Intervention group (IG): Participants received dietary training and personalized advice to increase adherence to the Mediterranean diet, including increasing intake of whole grain cereals (≥5 svg/d); vegetables and dairy products (≥3 svg/d); fresh fruit (≥2 svg/d) including natural fruit juices; and legumes, nuts, fish, and white meat (≥3 svg/wk), as well as olive oil use for cooking and dressings. They also received olive oil (2 L/mo) and walnuts (450 g/mo).; - Control group (CG): Participants received usual care per institutional protocols.; Adherence: Mediterranean diet scores were similar between groups at baseline, but significantly increased in the IG at follow-up compared to the CG.; - Positive components: EVOO; walnuts; vegetables; fresh fruit; dairy products; whole grains; sofrito; legumes; fish; fatty fish; white meat; - Negative components: Refined grains; red meat; processed meat; soda drinks; commercial bakery foods, sweets, and pastries; butter, margarine, or cream; Outcomes:; PTB <37 GW | PTB <37 GW; Logistic regression; Risk difference (95% CI); OR (95% CI) according to ITT analysis; −1.1 (−4.6, 2.4); 0.83 (0.48, 1.46), p=0.53; OR (95% CI) according to PP analysis IG: Participants with high dietary adherence (3pt increase in diet score); 0.72 (0.37, 1.42), p=0.35 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI, Current HDP; Funding: “La Caixa” Foundation; Cerebra Foundation for the Brain Injured Child; The Agency for Management of University and Research Grants; Centro de Investigaciones Biomédicas en Red sobre Enfermedades Raras; Summary: In participants at high risk for SGA, Mediterranean-style DP supplemented with walnuts and EVOO did not reduce risk of PTB <37 GW compared to usual care in either the ITT or the PP analyses.
Dodd, 2019^35^; RCT, Parallel-arm, Australia, OPTIMISE; Analytic N=633 (Attrition: 1%); - Age (y): 31.53±4.76; - Race/Ethnicity (%):; White: 67.46; Asian: 15.01;; Indian, Pakistani, Sri Lankan: 8.06; Other: 9.47; - Socioeconomic position:; ○ SEIFA IRSD (%): Quintile 1 (most disadvantaged): 16.75; Quintile 5: 17.85; - Baseline BMI: Median (IQR): 22.20 (20.87, 23.60); - Current HDP (%):; ○ Gestational HTN: ~1.4; ○ PE/Eclampsia: ~2.5; - Current DM (%):; ○ GDM: 12.4; ○ T1 or T2 DM: 0.0; - Smoking (%): Smoker: 4.42 | LI vs SC; FFQ at: Trial entry (10-20 GW), 28 GW, and 36 GW; DP Description:; - Lifestyle Intervention (LI): Received 3 in-person visits and 3 phone calls with dietitian or research assistant at trial entry, and 20, 24, 28, 32, and 36 GW. Dietary advice was consistent with current Australian dietary standards, maintaining a balance of carbohydrates, fat, and protein, and encouraging reduced intake of energy dense and non-core foods high in refined carbohydrates and saturated fats. Participants were advised to increase their intake of fibre, and to consume 2 svg/d fruit, 5 svg/d vegetables and 3 svg/d dairy.; - Standard Care (SC): Received antenatal care according to hospital guidelines, which did not include information relating to dietary intake, physical activity or weight gain during pregnancy.; Adherence: HEI scores from FFQ did not differ at baseline, but were higher in LI at 28 GW and 36 GW. Physical activity scores did not differ at either follow-up.; Outcomes:; PTB <37 GW | PTB <37 GW; Log binomial regression,; RR (95% CI); LI vs SC (Ref): 1.14 (0.64, 2.03), p=0.669 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI, DM in current pregnancy; Funding: The University of Adelaide; Lloyd Cox Strategic Research Excellence Award; NHMRC Practitioner Fellowship; Summary: Randomization to a dietitian-led dietary and lifestyle intervention based on the Australian Guide to Healthy Eating, compared to standard antenatal care, did not affect risk of PTB.
Gallagher, 2018^36^; RCT, United States, LIFT; Analytic N=196 (Attrition: 7%); - Age (y): LI: 33.8±4.0; UC: 33.8±4.7; - Race/Ethnicity (%):; ○ LI: Not Hispanic/Latina: 69; Hispanic: 30 White: 46; Other: 25; Black: 24; >1 Race: 5; Unknown: 1; ○ UC: Not Hispanic/Latina: 76; Hispanic: 24 White: 48; Black: 24; Other: 21; >1 Race: 8; Unknown: 0; - Socioeconomic position:; ○ Education (%): ≤HS diploma: LI: 4.0; UC: 3.0; College degree: LI: 44; UC: 37; Postgraduate work: LI: 37; UC: 49; ○ Annual family income (%): ≤24,999: LI: 3.0; UC: 7.0; 75k-149k: LI: 36; UC: 33; ≥150k: LI: 29; UC: 32; - Pre-pregnancy BMI: LI: 30.1±4.1; UC: 30.7±5.0 (%): 25-29.9: LI: 62; UC: 57; >30: LI: 38; UC: 43; - Current DM (%):; ○ T1 or T2 DM: 0.0; ○ GDM: LI: 10.3; UC: 6.1; - Smoking (%): 0.0 | LI vs UC; 24 HR at: 12-15.6, 36 GW; DP Description:; - Lifestyle Intervention (LI): Diet modification and increased physical activity, along with behavioral and social support strategies delivered in individual sessions by study counselors. Focus was on GWG control as recommended by 2009 IOM guidelines.; - Usual Care (UC): A single 20-30 minute ‘Introduction’ immediately following randomization. Participants were invited to attend UC group meetings once every 8 wk through delivery; Adherence: No differences in HEI-2010 scores between groups at baseline. HEI-2010 was significantly higher in the LI group compared to the UC group at 36 GW. Between group change from baseline was also statistically significantly higher in the LI group compared to the UC group.; Outcomes:; PTB: <37 GW, <32 GW | 32 to <37 GW; Chi-squared test, n (%) LI: 3 (3); UC: 7 (7); <32 GW; LI: 2 (2); UC: 0 (0) p=0.17 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI, DM in current pregnancy; Funding: NIH; NIDDK; NHLBI; NICHD; NCCIH; ORWH; OBSSR; The Indian Health Service; Summary: A GWG control intervention with higher alignment with HEI-2010 did not have an effect on risk of PTB <37 GW or <32 GW when compared to a control group with lower alignment with HEI-2010.
Khoury, 2005^37^; RCT, Norway, CARRDIP; Analytic N=290 (Attrition: 0%); - Age (y): ~29.7; Range: 21-38; - Race/Ethnicity (%): White: 100; - Socioeconomic position: Education: ~82.1% >12 y; - Pre-pregnancy BMI: TM2: ~24.3±2.8; - Current HDP (%): Chronic HTN: 0.0; - Current DM (%): Pre-existing DM: 0.0; - Smoking (%):Nonsmokers: 100 (Previous smokers had to have quit ≥5y before inclusion) | Intervention diet vs Control diet; At: BL, 24 GW, 30 GW, and 36 GW; DP Description:; Women randomly allocated to usual or intervention diet and asked to follow assigned diet until delivery Intervention group received cooking lessons to implement special foods (eg, legumes, olive oil); - Intervention diet: dietician encouraged intake of fatty fish, vegetable oils, especially olive oil and rapeseed oil, nuts, nut butters, margarine based on olive- or rapeseed oil, and avocado to replace meat, butter, cream, and fatty dairy products; ≥6/d fresh fruits and vegetables; intake of dairy products in the form of skimmed or low-fat products (skimmed milk, fat-reduced cheese, and yogurt) in place of full fat products; 2/wk meat for a main meal and legumes, vegetable main dishes, fatty fish, or poultry with the fat trimmed off on the other days; ≤2 c/d coffee; - Control diet: subjects asked to consume their usual diet based on Norwegian foodstuffs, and not to introduce more oils or low-fat meat and dairy products than usual; Adherence: assessed by weighed dietary records:; - Intervention diet: included significantly more fish and fish products; fatty fish and fish products; rapeseed-based margarine; oils; olive oil; rapeseed oil; nuts, olives, and seeds; vegetables; and fruits, when compared to the control diet; - Control diet: included significantly more fatty milk, meat and meat products, fatty minced meat, butter, and hard margarines, when compared to the intervention diet; Outcomes:; PTB <37 GW | PTB <37 GW; Logistic Regression; RR (95% CI); Intervention: 0.10 (0.01, 0.77); Control: Ref; p=0.006; PTB, Excluding the 3 cases of PE with PTB; Logistic Regression; RR (95% CI); Intervention: 0.06 (0.02, 0.09); Control: Ref; p=0.004 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Funding: The Norwegian Council on Cardiovascular Disease; Summary: The intervention diet resulted in a significantly reduced risk of preterm delivery.
Melero, 2020^38^; Non-RCT, Spain, St. Carlos GDM prevention study; Analytic N=544 (Attrition: 9%); - Age (y): CG: 31.3±5.6; IG: 31.7±5.4; - Race/Ethnicity (%): Hispanic: 100; - Socioeconomic position:; ○ Education (%): Elementary: CG: 19.7; IG: 12.6; Secondary: CG: 47.2; IG: 46.2; University: CG: 31.7; IG: 40.6; Unknown: CG: 1.4; IG: 0.7; ○ Unemployed (%): CG: 69.0; IG: 67.8; - Pre-pregnancy BMI: CG: 24.4±4.0; IG: 24.1±3.4; - Current HDP (%): CG: 4.9; IG: 2.8; - Current DM (%): CG: 34 (25.8); IG:19 (14.8); CG vs IG: p=0.021; - Smoking (%): CG: 0.7; IG: 0.7 | IG vs CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; The intervention group (IG), control group (CG), and real world group (RW) all given the same basic MedDiet recommendations: ≥2 servings/d vegetables, ≥3 servings/d fruit (avoiding juices), 3 servings/d skimmed dairy products, wholegrain cereals, 2-3 servings legumes/wk, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals.; - IG and RW also recommended to consume ≥40 mL/d of EVOO and nuts ≥3d/wk. IG was provided with 10 L EVOO and 2 MOBA roasted pistachios at 12-14 GW and 24-28 GW. RW was not provided with EVOO or pistachios.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ between the groups at baseline. Scores significantly increased over time in the IG and RW, while no changes in the CG were observed. Scores remaining significantly higher in the IG and RW compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: vegetables; dishes with tomato sauce (tomato, garlic, onion, leek, olive oil); pulses; nuts; fish; white meat over red meat; olive oil; olive oil as principal cooking fat.; - Negative components: commercial pastries; red meat or sausages; animal fat; SSB; - Alcohol and fruit (including juice) component excluded; Outcomes:; PTB <37 GW | PTB <37 GW; Chi-square test, n (%); IG vs CG: 4 (3.1) vs 8 (6.1), p=0.203 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Greater alignment with a MedDiet supplemented with EVOO and pistachios in a trial (IG) or real-world (RW) setting did not impact risk of preterm delivery compared to lower alignment with a MedDiet in a trial setting (CG).
Van Horn, 2018^39^; RCT, United States, MOMFIT; Analytic N=251 (Attrition: 11%); - Age (y): IG: 33±4; UC: 34±4; - Race/Ethnicity (%):; ○ White: IG: 56.4; UC: 70.2; ○ Black or African American: IG: 24.3; UC: 14.2; ○ Other: IG: 19.3; UC: 15.6; - Socioeconomic position:; ○ Total family income (%); ○ <$20k: IG: 3.6; UC: 5.7; ○ $20k−<$50k: IG: 12.4; UC: 13.5; ○ $50k−<$75k: IG: 12.4; UC: 13.5; ○ $75k−<$100k: IG: 13.9; UC: 9.9; ○ $100k−<$150k: IG: 24.8; UC: 27.7; ○ $150k−<$200k: IG: 16.8; UC: 10.6; ○ ≥$200k: IG: 16.1; UC: 19.2; - Pre-pregnancy BMI: IG: 31±4; UC: 31±4; - Current HDP (%): Family history of high blood pressure IG: 67.9; UC: 75.2; - Current DM (%): 0% prior diagnosis of diabetes of HbA1c >6.5%; - Family history of diabetes: IG: 51.4; UC: 59.6 Smoking (%): 0% | Intervention Group vs Usual Care; 24 HR at: 15 GW, 36 GW; DP Description:; MAMA-DASH: Higher low-fat milk and dairy products, fish, skinless poultry, lean meat and vegetable protein, unsaturated fats, fiber-rich whole grains, fruits, vegetables, and legumes. Lower SSB, other sweets, and non-nutrient-dense snack foods was discouraged.; Caloric restriction to meet GWG, following nutrition guidelines for pregnant women, including avoidance of fish considered higher in mercury, inclusion of calciumrich, vitamin D−enriched dairy, or calcium-fortified nondairy products; Adherence: at 36 GW; Median (IQR); - Dixon DASH: Intervention group (IG): 4(3, 4); Usual care (UC): 3(3, 4), p=0.01; - Fung DASH: IG: 27(25, 30); UC: 26(22, 29), p=0.005; - HEI-2010: IG: 70(62, 77); UC: 63(56, 75), p=0.002; Outcomes:; PTB <37 GW | PTB <37 GW; Regression model, n (%); IG: 6 (4.3), p=0.13; UC: 12 (8.8) | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Funding: NIDDK, NHLBI; NICHD; NCCIH; ORWH; OBSSR; the Indian Health Service; Summary: Randomization to DASH and physical activity coaching compared to usual care was not associated with PTB.
Zhao, 2022^40^; RCT, Parallel-arm, China, People’s Hospital of Zhengzhou University; Baseline N=560; Analytic N=500 (Attrition: 11%); - Age (y): CG: 28±5.2; IG: 29.4±5.6; - Socioeconomic position:; ○ Employed (%): CG: 75.2; IG: 46.4; ○ Education (%) HS: CG: 10.0; IG: 10.8; University: CG: 37.2, IG: 38.8; Unknown: CG: 6.4; IG: 1.2; - Pre-pregnancy BMI: CG: 23.3±3.9; IG: 22.8±3.4; - Current DM (%): GDM: CG: 20.4; IG: 13.6, p=0.042; - Smoking (%): Current: CG: 2.4; IG: 2 | CG vs IG; FFQ at: 8-12 GW, 24-28 GW, 36-38 GW; DP Description:; - Both groups: MedDiet (vegetables, fruits, skimmed dairy foods, whole grain cereals, legumes, fish; avoid refined grains, baked goods, soft drinks, juices, junk food, precooked meat, pre-sliced slices of bread) and walking 30 min/d recommended; - Intervention group (IG): Recommended to consume ≥40 ml/d EVOO and 25-30 g/d roasted pistachios recommended; Weekly visits with a dietitian; - Control group (CG): Recommended to restrict dietary fat, including extra virgin coconut oil and dry fruits, by the midwives.; Adherence: MEDAS scores did not differ at baseline. Scores significantly increased over time in both groups, but the IG had significantly higher scores than the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries; Outcomes:; PTB <37 GW | PTB <37 GW (%); Chi-square; IG: 1.2, p=0.018; CG: 4.8; Repeated Analysis Of Variance; RR (95% CI); 0.25 (0.07, 0.87), p=0.030 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Pre-pregnancy BMI, Current HDP; Funding: No Funding received; Summary: A MedDiet with recommended additional EVOO and pistachios lowers the risk of PTB.
NRCT
Melero, 2020^38^; Non-RCT, Spain, St. Carlos GDM prevention study; Analytic N=544 (Attrition: 9%); - Age (y): CG: 31.3±5.6; RW: 31.4±5.7; - Race/Ethnicity (%): Hispanic: 100; - Socioeconomic position:; ○ Education (%): Elementary: CG: 19.7; RW: 11.2; Secondary: CG: 47.2; RW: 50.8; University: CG: 31.7; RW: 35.5; Unknown: CG: 1.4; RW: 2.5; ○ Unemployed (%): CG: 69.0; RW: 73.3; - Pre-pregnancy BMI: CG: 24.4±4.0; RW: 23.4±3.6; RW vs CG, p=0.033; - Current HDP (%): CG: 4.9; RW: 2.5; - Current DM (%): CG: 34 (25.8); RW: 38 (13.4); RW vs CG: p=0.011; - Smoking (%): CG: 0.7; RW: 1.6 | RW vs CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; The intervention group (IG), control group (CG), and real world group (RW) all given the same basic MedDiet recommendations: ≥2 servings/d vegetables, ≥3 servings/d fruit (avoiding juices), 3 servings/d skimmed dairy products, wholegrain cereals, 2-3 servings legumes/wk, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals.; - IG and RW also recommended to consume ≥40 mL/d of EVOO and nuts ≥3d/wk. IG was provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW. RW was not provided with EVOO or pistachios.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ between the groups at baseline. Scores significantly increased over time in the IG and RW, while no changes in the CG were observed. Scores remaining significantly higher in the IG and RW compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: vegetables; dishes with tomato sauce (tomato, garlic, onion, leek, olive oil); pulses; nuts; fish; white meat over red meat; olive oil; olive oil as principal cooking fat.; - Negative components: commercial pastries; red meat or sausages; animal fat; SSB; Alcohol and fruit (including juice) component excluded; Outcomes:; PTB <37 GW | PTB <37 GW; Chi-square test; n (%); RW vs CG: 15 (5.3) vs 8 (6.1), p=0.337 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Greater alignment with a MedDiet supplemented with EVOO and pistachios in a trial (IG) or real-world (RW) setting did not impact risk of preterm delivery compared to lower alignment with a MedDiet in a trial setting (CG).
Index/Score
Chia, 2018^4^; PCS, Singapore, GUSTO; Analytic N=1,051; - Age (y): Quintile 1: 28.9±5.4; Quintile 5: 31.6±4.6, p<0.001; - Race/Ethnicity (%): Chinese: Quintile 1: 44; Quintile 5: 65; Malay: Quintile 1: 43; Quintile 5: 13; Indian: Quintile 1: 12; Quintile 5: 22; - Socioeconomic position:; ○ Education (%): ≤Secondary: Quintile 1: 40; Quintile 5: 17; University: Quintile 1: 20; Quintile 5: 55, p<0.001; ○ Household Income (%): <2000 SGD: Quintile 1: 24; Quintile 5: 7; >6000 SGD: Quintile 1: 18; Quintile 5: 43, p<0.001; - Pre-pregnancy BMI: Quintile 1: 22.8±4.4; Quintile 5: 22.0±3.5, p=0.04; - Current HDP (%): Chronic HTN, Gestational HTN, PE, or GDM: 26.5; - Current DM (%): T1 DM: 0.0; - Smoking (%): Quintile 1: 4.8; Quintile 5: 0.5, p<0.001 | HEI-SGP (quintiles of alignment); 24 HR or 3-d food diaries at: 26–28 GW; DP Description:; HEI-SGP; - Positive components: Total fruit (including 100% juice); Whole fruit; Total vegetables (excluding starchy vegetables); Dark green leafy and orange vegetables; Total rice and alternatives (including products made from flour and starchy tuber vegetables); Whole grains; Dairy (including fortified soy beverages); Total protein foods (excluding dairy); Use of antenatal supplements containing iron, folate, and calcium; - Negative components: Total Fat; Total Saturated Fat; Outcomes:; PTB <37 GW | PTB <37 GW; Logistic regression; OR (95% CI); 0.91 (0.75, 1.11); Alternately excluding one component of the HEI-SGP score did not substantially change results | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: Infant sex; GWG up to 26-28 GW; Height; total energy intake; Physical activity; Alcohol use; Funding: The Singapore National Research Foundation; The Singapore Institute for Clinical Sciences, Agency for Science Technology and Research (A*STAR), The NIHR Southampton Biomedical Research Centre; The European Union’s Seventh Framework Program; The EarlyNutrition and ODIN projects; Summary: Alignment with the HEI-SGP was not associated with risk of PTB.
Fulay, 2018^7^; PCS, United States, Project Viva; Analytic N=1,743; - Age (y): Age (y): 32.2±4.9; - Race/Ethnicity (%):White: 71.9; Black: 12.3; Hispanic: 6.5; Asian: 5.6; Other: 3.6; - Socioeconomic position:; ○ Household income (%): <$20k/y: 3.1; >$70k/y: 60.1; ○ Education (%): Primary: 9.4; ≥College: 32.0; - Pre-pregnancy BMI: 25-<30: 21.7; ≥30: 12.9; - Current HDP (%): HDP: 10.7; - Current DM (%):; ○ Current GDM: 5.2; ○ Current T1 or T2 DM: 0.0; - Smoking (%): 10.9 | DASH & DASH OMNI (continuous alignment); FFQ at: ~11 GW; DP Description:; [underlined: DASH]; - Positive components: fruits; vegetables; whole grains; nuts/legumes; low-fat dairy; - Negative components: sodium; SSB; red and/or processed meats; [underlined: DASH OMNI]; - Positive components: fruits; vegetables; whole grains; nuts/legumes; low-fat dairy; MUFA and PUFA; - Negative components: sodium; SSB; red and/or processed meats; Outcomes:; PTB <37 GW | PTB <37 GW; Logistic regression; OR (95% CI); [underlined: DASH:] 0.99 (0.95, 1.03), p≥0.05; [underlined: DASH OMNI]: 0.97 (0.93, 1.02), p≥0.05; Additionally adjusting for Western and Prudent DP did not substantially alter the results | Key confounders accounted for:; Parity, magnitude, or precision of the results, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Prepregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: GWG until FFQ; total energy intake; Funding: NIH; Summary: Alignment with DASH or DASH OMNI was not associated with risk of PTB.
Haugen, 2008^9^; PCS, Norway, MoBa; Exposure N=569, Comparator N=1-4 criteria: 25,397 (1 criterion: ~2,159, 2: ~8,308, 3: 10,737, 4: ~4,128); 0: 159; - Age (y): ~ 30.7; Range: 21-38; - Socioeconomic position: Educational level between women who were most compliant was higher than those who were partially compliant and least compliant, p<0.001; - Pre-pregnancy BMI:; ○ Fulfilling all MD criteria: 23.0; ○ Fulfilling 1-4 MD criteria: 23.8; ○ Fulfilling none of the MD criteria: 23.7; - Smoking (%): Non-smokers: 100 | Met all 5 MD criteria vs 0 MD criteria; Met all 5 MD criteria vs 1-4 MD criteria; FFQ at: 17-24 GW; DP Description:; Mediterranean Diet Index (MD): all 5 criteria had to be met: ≥5 svg/d of veg or fruit, ≥2 svg/wk fish, olive/canola/rapeseed oil for cooking and dressing, ≤2 svg/wk red meat, ≤2 c/d coffee; Outcomes:; PTB: <37 GW; Late PTB: 35-36 GW; Early PTB: <35 GW | PTB; Logistic regression; OR (95% CI); [underlined: 5 vs 0 criteria]: 0.73 (0.32, 1.68); [underlined: 5 vs 1-4 criteria]: 1.06 (0.71, 1.58); Early PTB; Logistic regression; OR (95% CI); [underlined: 5 vs 0 criteria]: 0.93 (0.16, 5.37); [underlined: 5 vs 1-4 criteria]: 0.80 (0.40, 1.62); Late PTB; Logistic regression; OR (95% CI); [underlined: 5 vs 0 criteria]: 0.66 (0.25, 1.69); [underlined: 5 vs 1-4 criteria]: 1.24 (0.77, 2.0) | Key confounders accounted for:; Parity, Smoking, Age, Socioeconomic position, Pre-pregnancy BMI; Other covariates: maternal height; Funding: Norwegian Ministry of Health, NIH, Norwegian Research; Council/FUGE; Summary: No association between alignment with the MD and risk of PTB
Hillesund, 2014^11^; PCS, Norway, MoBa; Exposure N=High alignment: 27,161; Medium alignment: 25,532, Comparator N=19,344; - Age (y): 30.1±4.6; ○ (%) <25: 11.5; 25-29: 33.9; 30-34: 42.4; ≥35: 12.2; - Socioeconomic position:; Education (%): ≤12 y: 31.1; 13-16y: 41.4; ≥17 y: 25.3; - Pre-pregnancy BMI: 24.0±4.3; ○ (%): <18.5: 3.0; 18.5-24.9: 64.1; 25-29.9: 21.1; 30-34.9: 6.7; ≥35: 2.5; - Current HDP (%): Chronic HTN: 0.5; - Current DM (%):; ○ DM (all categories): 1.5;; ○ Pregestational DM: 0.6;; ○ GDM: 0.9; - Smoking (%): In midpregnancy: No: 91.3; Occasional: 2.7; Daily: 5.2 | NND High (score: 6-10) or Medium (score: 4-5) vs Low (score: 0-3) alignment; FFQ at: ~22 GW; DP Description:; New Nordic Diet (NND); Positive components: (i) eating ≥24 main meals/wk; (ii) vegetables ≥5 times/week; (iv) eating cabbage ≥2 times/week; (v) eating potatoes ≥one-third of total occasions of eating potatoes, rice or pasta; (vi) choosing whole grain bread more often than refined bread; (vii) eating oatmeal ≥monthly; (viii) eating fish/game/berries about 2 times/week; (ix) drinking milk more often than juice; and (x) drinking ≥6 times as much water as SSB; Outcomes:; PTB: 22-37 GW (all and spontaneous) | PTB; Multivariate Logistic Regression; OR (95% CI); High vs Low (Ref): 0.90 (0.81, 0.98); Medium vs Low (Ref): NR; Spontaneous PTB; Multivariate Logistic Regression; OR (95% CI); High vs Low (Ref): 0.91 (0.80, 1.03); Medium vs Low (Ref): 1.06 (0.94, 1.19); Nulliparity; High vs Low (Ref): 0.77 (0.66, 0.89); Medium vs Low (Ref): 0.95 (0.85, 1.12); Multiparity; High vs Low (Ref): 1.24 (1.00, 1.53); Medium vs Low (Ref): 1.28 (1.03, 1.58); With pre-gestational DM; High vs Low (Ref): 0.89 (0.79, 1.01); With GDM; High vs Low (Ref): 1.44 (0.41, 5.13) | Key confounders accounted for:; Parity, Smoking, Age, Socioeconomic position, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: Exercise during pregnancy, chronic hypertension, and energy intake. Marital status, maternal height, and dietary supplement use changed the parameter estimates <10%, and thus removed from models; Funding: Norwegian Ministry of Health and the Ministry of Education and Research; NIEHS; NINDS; the Norwegian Research Council/FUGE. The present study was funded by the University of Agder.; Summary: High vs low alignment with the NND was associated with a reduced risk of PTB. High vs low alignment was also associated with reduced risk of spontaneous PTB among nulliparous women. High vs low alignment was associated with higher risk of spontaneous PTB among multiparous women.; Alignment with the NND was not associated with spontaneous PTB in the whole sample or among those with pregestational-DM or GDM.
Hillesund, 2018^10^; PCS, Norway, NFFD; Analytic N=587; - Age (y): 28.0±4.4; ○ (%): ≥35: 6.8; - Race/Ethnicity (%): “Predominantly White”; - Socioeconomic position:; ○ Education (%): ≤12y: 31.8; ≥16y: 35.5; ○ Occupation (%): Work outside home: 84.2; Student: 8.7; Unemployed: 3.9; Sick leave/disabled: 1.9; Homemaker: 1.4; ○ Income (%): ≤400k NOK: 31.2; >700k NOK: 34.4; NR: 6.6; - Pre-pregnancy BMI: (%) 25-29.9: 20.2; ≥30: 7.6; - Current HDP (%):; ○ PE: 4.3; ○ Severe PE: 2.6; - Current DM (%):; ○ Pre-existing DM: 0.0; ○ GDM: 9.1; - Smoking (%): 3.9 | NFFD diet (continuous alignment); FFQ at: ~15 GW; DP Description:; - Positive components: regular meals; drinking water when thirsty; vegetables w/ dinner; fruits and vegetables between meals; reading nutrition labels before buying; - Negative components: sweets and snacks without appreciation; large portion sizes of unhealthy foods; added sugar; salt; eating beyond satiety; Outcomes:; PTB; Defined as GA at birth <37 GW | PTB <37 GW; Multivariate logistic regression; OR (95% CI); [underlined: All participants]; 0.77 (0.64, 0.92), p=0.005; Additionally adjusted for PA: 0.82 (0.67, 0.99), p=0.038; [underlined: PE cases excluded (n=555)]; 0.77 (0.62, 0.96), p=0.018; Additionally adjusted for PA: 0.81 (0.64, 1.02), p=0.068; Sensitivity analysis confined to the control group in the original trial did not materially impact the results | Key confounders accounted for:; Parity, Smoking, Age, Socioeconomic position, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: Marital status; Randomization assignment; Funding: South-Eastern Norway Regional Health Authority; The municipalities of southern Norway; The University of Agder; Summary: Greater alignment with the NFFD diet was associated with reduced risk of PTB, including when excluding PE cases. The relationship was attenuated when excluding PE cases and adjusting for PA.
Li, 2021^14^; PCS, United States, NICHD Fetal Growth Studies– Singletons; Analytic N=Gestational HTN: 813 GW: 1,505; 16-22 GW: 1,682; 24-29 GW: 1,652; PE: 8-13 GW: 1,502; 16-22 GW: 1,685; 24-29 GW: 1,649; - Age (y):; ○ AHEI: Q1: 25.9±5.57; Q4: 30.5±4.84, p<0.001; ○ aMED: Q1: 26.4±5.70; Q4: 29.9±5.29, p<0.001; ○ DASH: Q1: 25.5±5.43; Q4: 30.4±4.84, p<0.001; - Race/Ethnicity (%):; ○ AHEI: NHB: Q1: 49.1; Q4: 14.9; Hispanic: Q1: 24.1; Q4: 26.2; NHW: Q1: 17.9; Q4: 27.5; AAPI: Q1: 8.9; Q4: 31.4, p<0.001; ○ aMED: NHB: Q1: 39.9; Q4: 22.4; Hispanic: Q1: 28.7; Q4: 25.4; NHW: Q1: 20.5; Q4: 26.0; AAPI: Q1: 11.0; Q4: 26.3, p<0.001; ○ DASH: NHB: Q1: 55.3; Q4: 14.0; Hispanic: Q1: 21.5; Q4: 29.2; NHW: Q1: 10.1; Q4: 37.5; AAPI: Q1: 13.1; Q4: 19.3, p<0.001; - Education (%):; ○ AHEI: <HS: Q1: 12.2; Q4: 9.4; HS/equivalent: Q1: 27.5; Q4: 12.4; Graduate degree: Q1: 6.9; Q4: 28.7, p<0.001;; ○ aMED: <HS: Q1: 14.6; Q4: 8.3; HS/equivalent: Q1: 27.8; Q4: 12.4; Graduate degree: Q1: 9.0; Q4: 26.0, p<0.001;; ○ DASH: <HS: Q1: 14.8; Q4: 8.5; HS/equivalent: Q1: 31.0; Q4: 10.5; Graduate degree: Q1: 5.6; Q4: 30.6, p<0.001; - Pre-pregnancy BMI: (%):; ○ AHEI: 25-29: Q1: 29.8; Q4: 21.3; ≥30: Q1: 20.3; Q4: 11.4, p<0.001; ○ aMED: 25-29: Q1: 30.1; Q4: 22.4; ≥30: Q1: 21.3; Q4: 9.7, p<0.001; ○ DASH: 25-29: Q1: 29.6; Q4: 25.1; ≥30: Q1: 19.0; Q4: 11.6, p=0.01; - Current HDP (%): Gestational HTN: 3.5; PE: 3.5; - Current DM (%): Pre-existing DM: 0.0; GDM: 5.0; - Smoking (%): Pre-pregnancy BMI <30: 0.0 | AHEI, aMED, & DASH (quartiles of alignment); FFQ at: 8-13 GW; 24HR at 16-22 GW, 24-29 GW; DP Descriptions:; [underlined: AHEI]; - Positive components: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA; - Negative components: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Sodium; - Alcohol and trans-fat components removed; [underlined: aMED]; - Positive components: Vegetables; Fruit; Nuts; Fish; Lean Meat (poultry, lean beef); - Negative components: Red and Processed Meat; Sodium. Neutral: Grains and Starches; Dairy Foods; - Alcohol component removed; [underlined: DASH]; - Positive components: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy; - Negative components: Red and Processed Meat; Sweetened Beverages; Sodium; Outcomes:; PTB <37 GW | PTB <37 GW; Log-binomial regression; RR (95% CI); AHEI; [underlined: 8-13 GW]; Q2 vs Q1 (Ref): 1.56 (0.89, 2.73), p=NS; Q3 vs Q1 (Ref): 1.18 (0.64, 2.18), p=NS; Q4 vs Q1 (Ref): 0.78 (0.39, 1.57), p=NS; p for trend=0.40; [underlined: 16-22 GW]; Q2 vs Q1 (Ref): 1.08 (0.66, 1.76), p=NS; Q3 vs Q1 (Ref): 1.01 (0.60, 1.69), p=NS; Q4 vs Q1 (Ref): 0.76 (0.42, 1.36), p=NS; p for trend=0.34; [underlined: 24-29 GW]; Q2 vs Q1 (Ref): 0.63 (0.36, 1.12), p=NS; Q3 vs Q1 (Ref): 0.88 (0.52, 1.50), p=NS; Q4 vs Q1 (Ref): 0.55 (0.29, 1.04), p=NS; p for trend=0.14; aMED; [underlined: 8-13 GW]; Q2 vs Q1 (Ref): 0.78 (0.47, 1.30), p=NS; Q3 vs Q1 (Ref): 0.49 (0.24, 1.01), p=NS; Q4 vs Q1 (Ref): 0.50 (0.25, 1.01), p=NS; p for trend=0.03; [underlined: 16-22 GW]; Q2 vs Q1 (Ref): 1.29 (0.78, 2.14), p=NS; Q3 vs Q1 (Ref): 1.19 (0.70, 2.04), p=NS; Q4 vs Q1 (Ref): 1.06 (0.61, 1.84), p=NS; p for trend=0.93; [underlined: 24-29 GW]; Q2 vs Q1 (Ref): 0.65 (0.36, 1.19), p=NS; Q3 vs Q1 (Ref): 1.01 (0.59, 1.72), p=NS; Q4 vs Q1 (Ref): 0.92 (0.52, 1.61), p=NS; p for trend=0.93; DASH; [underlined: 8-13 GW]; Q2 vs Q1 (Ref): 0.70 (0.40, 1.21), p=NS; Q3 vs Q1 (Ref): 1.00 (0.57, 1.77), p=NS; Q4 vs Q1 (Ref): 0.56 (0.28, 1.13), p=NS; p for trend=0.21; [underlined: 16-22 GW]; Q2 vs Q1 (Ref): 0.92 (0.57, 1.48), p=NS; Q3 vs Q1 (Ref): 0.49 (0.26, 0.93), p<0.05; Q4 vs Q1 (Ref): 0.79 (0.44, 1.40), p=NS; p for trend=0.21; [underlined: 24-29 GW]; Q2 vs Q1 (Ref): 0.69 (0.40, 1.17), p=NS; Q3 vs Q1 (Ref): 0.58 (0.32, 1.07), p=NS; Q4 vs Q1 (Ref): 0.50 (0.26, 0.96), p<0.05; p for trend=0.03 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Prepregnancy BMI; Other covariates: Marital status; Family history of DM; Sleep duration; total energy intake; Physical activity; Funding: NICHD; AARA; Summary: Greater alignment with aMED at 8-13 GW, but not at 16-22 GW or 24-29 GW, was associated with reduced risk of PTB.; Greater alignment with DASH at 24-29 GW was associated with reduced risk of PTB. The third quartile of alignment with DASH at 16-22 GW was associated with reduced risk of PTB compared to the lowest quartile, but all other associations between DASH at 16-22 GW and risk of PTB were statistically non-significant. Associations between DASH at 8-13 GW and risk of PTB were statistically non-significant.; Alignment with AHEI was not associated with risk of PTB.
Makarem, 2022^16^; PCS, United States, nuMoM2b; Analytic N=7,798; - Age (y): 27.4±5.5; ○ (%): ≥35: 9.7; - Race/Ethnicity (%): NHW: 63.9; Hispanic: 16.6; NHB: 10.5; Asian: 4.3; Other: 4.6; - Socioeconomic position:; ○ Education (%): <HS: 5.7; ≥Bachelor’s: 55.6; - Baseline BMI ≥30 (%): 19.5; - Current HDP (%):; ○ Chronic HTN: 0.0; Gestational HTN: ~14%; - Current DM (%): 3.8; - Smoking (%): Ever: 41.4 | aMED (categorical alignment, quintiles of alignment); FFQ at: 6-<14 GW; DP Description:; - Positive components: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA:SFA; - Moderate component: Alcohol; - Negative component: Red and Processed Meat; Outcomes:; PTB <37 GW (All, Spontaneous, Iatrogenic) | PTB-Composite; Multivariable logistic regression; OR (95% CI); Moderate vs Low (Ref): 0.95 (0.74, 1.21), p=0.69; High vs Low (Ref): 0.91 (0.69, 1.20), p=0.52; Quintile 2 vs Quintile 1 (Ref): 1.04 (0.80-1.34), p=0.78; Quintile 3 vs Quintile 1 (Ref): 0.92 (0.65-1.30), p=0.65; Quintile 4 vs Quintile 1 (Ref): 0.81 (0.55-1.17), p=0.26; Quintile 5 vs Quintile 1 (Ref): 1.06 (0.74-1.51), p=0.74; p for trend=0.66; PTB-Iatrogenic; Multivariable logistic regression; OR (95% CI); Moderate vs Low (Ref): 0.98 (0.66, 1.46), p=0.92; High vs Low (Ref): 0.80 (0.49, 1.27), p=0.34; PTB-Spontaneous; Multivariable logistic regression; OR (95% CI); Moderate vs Low (Ref): 0.94 (0.69, 1.26), p=0.67; High vs Low (Ref): 0.98 (0.70, 1.37), p=0.91 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Prepregnancy BMI; Other covariates: Marital status; Family history of cardiovascular disease; Funding: NIH/ORWH BIRCWH; NIH/NHLBI; NIH/NICHD; OBSSR; NCATS; NIH/NIA; the Barbra Streisand Women’s Cardiovascular Research and Education Program; the Erika J. Glazer Women’s Heart Research Initiative; AHA; NIH/NINDS; the Gerstner Family Foundation; Summary: Alignment with aMed was not associated with risk of PTB, either spontaneous, iatrogenic, or combined.
Martin, 2015^18^; PCS, United States, PIN; Analytic N=3,143; - Age (y): (%) <25y: 33.6%; 25-29: 28.1%; 30-34: 25.9%; ≥35: 12.4%; - Race/Ethnicity (%): 71.8% Non-black; 28.2% Black; - Socioeconomic position:; ○ Education (%): <HS: 12.4; HS: 22.7; >HS: 64.9; ○ FPL (%): <185%: 41.2; 185-350%: 20.2; >350%: 38.6; - Pre-pregnancy BMI: (%) <18.5: 4.8; 18.5-24.9: 54.3; 25.0-29.9: 19.3; ≥30: 21.5; - Smoking (%): Nonsmoker: 80.7; Smoker: 19.3 | DASH score (quartiles of alignment); FFQ at: 26-29 GW; DP Description:; - Positive components: fruits, vegetables, nuts and legumes, low-fat dairy, and whole grains; - Negative components: sodium, red and processed meats, and sweetened beverages; Outcomes:; PTB: <37 GW; Spontaneous PTB: preceded by either preterm labor or premature rupture of the membranes resulting in delivery; Medically indicated: induction of labor or cesarean delivery without labor | PTB; Logistic Regression; OR (95% CI); Q4 vs Q1 (Ref): 0.59 (0.40, 0.85); Q3 vs Q1 (Ref): 0.96 (0.72, 1.29); Q2 vs Q1 (Ref): 0.85 (0.63, 1.16); Spontaneous PTB; Logistic Regression; OR (95% CI); DASH:; Q4 vs Q1 (Ref): 0.58 (0.36, 0.95); Q3 vs Q1 (Ref): NS; Q2 vs Q1 (Ref): NS; Medically indicated PTB; All comparisons: NS | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, HH income in model, Pre-pregnancy BMI; Other covariates: Energy intake, marital status; Funding: NIH; Summary: Higher alignment with the DASH DP was associated with reduced risk of PTB and with spontaneous PTB, but not medically indicated PTB.
Mikkelsen, 2008^20^; PCS, Denmark, DNBC; Exposure N=1,137, Comparator N=CG1: 33,853; CG2: 540; - Age (y): MD: 29.7±3.5; CG1: 29.3±3.8; CG2: 29.9±3.7; ○ Ages <21 y and >38 y excluded; - Pre-pregnancy BMI: MD: 22.3±2.5; CG1: 23.3±3.0; CG2: 23.7±3.0; ○ Pre-pregnancy BMI <19 and >32 excluded; - Current HDP (%): Chronic HTN: 0.0; - Smoking (%): Women who smoked excluded | MD vs CG1; MD vs CG2; FFQ at: 25 GW; DP Description:; Creation of Mediterranean diet (MD) group and two control groups:; - MD group met all of the below criteria; - Control group (CG) 1 met 1-4 criteria; - CG 2 met none of the criteria; Criteria to define Mediterranean diet: consumption of fish twice a week or more (lunch or dinner), intake of olive or rape seed oil, high consumption of fruits and vegetables (5 a day or more), meat (other than poultry and fish) at most twice a week, and at most 2 cups of coffee a day; Outcomes:; PTB: <37 GW; Early: PTB <35 GW; Late PTB: 35-36 GW | PTB; Logistic Regression; OR (95% CI); [underlined: MD vs CG1]: 0.92 (0.69, 1.24); [underlined: MD vs CG2]: 0.61 (0.35, 1.05); Early preterm; Logistic Regression; OR (95% CI); [underlined: MD vs CG1]: 0.58 (0.32, 1.06); [underlined: MD vs CG2]: 0.28 (0.11, 0.76); Late preterm; Logistic Regression; OR (95% CI); [underlined: MD vs CG1]: 1.11 (0.80, 1.55); [underlined: MD vs CG2]: 0.82 (0.43, 1.57) | Key confounders accounted for:; Parity, Smoking, Socioeconomic position: (5 groups, according to job description), and civil status (with or without cohabitant), Pre-pregnancy BMI; Other covariates: height; Funding: March of Dimes Birth Defects Foundation, Danish National Research Foundation, Danish Medical Research Council, Danish Health Foundation, and Danish Heart Foundation, the European Union, Pharmacy Foundation, Egmont Foundation, and Augustinus Foundation; Summary: Alignment with the MD was associated with a lower risk of early PTB versus CG2 but was not associated with risk of PTB or late PTB. Alignment with the MD was not associated with risk of PTB, early PTB, or late PTB versus CG1.
Navarro, 2019^22^; PCS, Ireland, Lifeways Cross-Generation Cohort Study; Analytic N=958; - Age (y): 30.1 ± 5.9; - Socioeconomic position:; ○ Education (%): <Tertiary: 51, ≥Tertiary: 49; ○ Household income (£/wk, %): <200: 14, >600£: 36; - Pre-pregnancy BMI: 23.8 ± 4.2; - Smoking (%): During pregnancy: 25 | HEI-2015 (tertiles of alignment; per 10pt increase); FFQ at: 12-16 GW; DP Description:; - Positive components: total fruits, whole fruits, total vegetables, greens and beans, total protein containing foods, seafood and plant proteins, whole grains, dairy, ratio of PUFAs and MUFAs to SFAs; - Negative components: refined grains, sodium, added sugars, saturated fats; Outcomes:; PTB <37 GW | PTB; Logistic regression; OR (95% CI); T2 vs T1 (Ref): 0.89 (0.41, 1.87); T3 vs T1 (Ref): 0.67 (0.31, 1.64); p trend: 0.23; Continuous (per 10 point increment): 0.63 (0.51, 1.10) | Key confounders accounted for:; Parity, Smoking, Age, Socioeconomic position: maternal and paternal SES, education status, household income, Pre-pregnancy BMI; Other covariates: marital status, alcohol consumption, energy intake, sex; Funding: Irish Health Research Board; Summary: Alignment with HEI-2015 was not associated with risk of PTB.
Parisi, 2020^24^; PCS, Italy, Luigi Sacco University Hospital; Analytic N=94; - Age (Median (range), y): 31 (18-43); - Socioeconomic position: Employed (%): 75; - Pre-pregnancy BMI (Median (range): 21.9 (15.6-39.5); - Current HDP (%): 3.2; - Current DM (%): GDM: 11.7; - Smoking (%): Periconceptional: 11.6 | FIGO Recommendations (<5 vs ≥5); Questionnaire at: 11-13 GW; DP Description:; - Positive components: Meat, fruit and vegetables, fish, dairy products, whole cereals, hemoglobin concentration, folic acid supplementation, iodized salt, sun exposure.; - Negative components: Sweets and snacks.; Outcomes:; PTB <37 GW (spontaneous) | PTB; RR (95% CI); <5 vs ≥5 (Ref): 1.44 (1.25, 1.65), p<0.05 | Key confounders accounted for:; Parity, Smoking, Age, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: GA at enrollment, fetal sex; Funding: None; Summary: Alignment with FIGO recommendations was associated with lower risk of PTB.
Robinson, 2021^26^; PCS, United States, nuMoM2b; Analytic N=7,365; - Race/Ethnicity (%): White: Term: 71.4, PTB: 64.8; Other/multiple: Term: 18.7, PTB: 19.7; Black: Term: 9.8, PTB: 15.4; - Socioeconomic position:; ○ Education (%): <HS: Term: 5.6, PTB: 7.6; Associate/ technical or Bachelor’s: Term: 41.2, PTB: 37.5; Master’s/ doctoral: Term: 26.0, PTB: 21.7; ○ Total family income (%) <$50k: Term: 29.4, PTB: 27.4; >$150k: Term: 20.2, PTB: 12.9; ○ Health insurance provider (%): Any government insurance: Term: 22.5, PTB: 29.4; Commercial: Term: 72.9, PTB: 66.5; Other: Term: 4.1, PTB: 3.6; - Pre-pregnancy BMI: (%); ○ <18.5: Term: 4.0, PTB: 4.0; ○ 25-<30: Term: 21.0, PTB: 22.9; ○ ≥30: Term: 17.5, PTB: 23.7; - Current HDP (%): HTN pre-pregnancy, recently requiring medication: Term: 0.7, PTB: 1.8; - Current DM (%): Diabetes pre-pregnancy, recently requiring medication: Term: 0.6, PTB: 3.0; - Smoking (%):; ○ Never smoker: Term: 58.8, PTB: 55.6; ○ Smoker, not in last month: Term: 36.6, PTB: 37.3; ○ Smoker, yes in last month: Term: 4.6, PTB: 6.5 | AHEI-2020 (continuous alignment); FFQ at: 6-13 GW; DP Description:; - Positive components: vegetables, fruit, whole grains, nuts and legumes, long-chain (omega-3) fats (EPA+DHA), PUFA.; - Negative components: SSB and fruit juice, red/processed meat, trans fat, sodium. Moderate intake of alcohol.; Outcomes:; PTB <37 GW | PTB by BMI category; Logistic regression; OR (95% CI); [underlined: <18.5]; 1.02 (0.992, 1.058), p=0.23; [underlined: 18.5-<25]; 0.99 (0.978, 0.999), p=0.10; [underlined: 25-<30]; 1.02 (1.005, 1.037), p=0.08; [underlined: ≥30]; 1.01 (0.991, 1.024), p=0.52; p for interaction: 0.04 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Socioeconomic position, Pre-pregnancy BMI, Current HDP; Other covariates: PA, marital status; Funding: NICHD; UC-Irvine; Northwestern University; Summary: Alignment with the AHEI-2010 was associated with risk of PTB but this varied by BMI category, with greater alignment tending to be associated with higher risk of PTB with BMI 25-<30 and tending to be associated with lower risk of PTB with BMI 18.5-<25, while it was not associated with PTB with BMI <18.5 or ≥30.
Yee, 2020^28^; PCS, United States, nuMoM2b; Analytic N=8,259; - Age (y): Q1: 23.9±5.2; Q4: 29.9±4.5, p<0.001; - Race/Ethnicity (%): NHW: Q1: 47.8; Q4: 74.4; NHB: Q1: 24.0; Q4: 2.8; Hispanic: Q1: 20.3; Q4: 11.9; Other: Q1: 6.3; Q4: 4.0; Asian: Q1: 1.5; Q4: 6.9, p<0.001; - Socioeconomic position:; ○ Public insurance (%): Q1: 50.7; Q4: 8.4, p<0.001; ○ Household income <200% FPL (%): Q1: 55.7; Q4: 12.4, p<0.001; ○ ≥Some college (%): Q1: 82.0; Q4: 98.8, p<0.001; - Pre-pregnancy BMI: Q1: 27.1±7.3; Q4: 24.9±4.9, p<0.001; - Current HDP (%):; ○ Chronic HTN: Q1: 3.3; Q4: 1.2, p<0.001; ○ HDP: Q1: 25.9; Q4: 20.3, p<0.001; - Current DM (%):; ○ Pregestational DM: Q1: 2.0; Q4: 0.8, p=0.018; ○ GDM: ~4.4; - Smoking (%): Ever used tobacco: Q1: 50.7; Q4: 36.6, p<0.001 | HEI-2010 (quartiles of alignment); FFQ at: 6-13 GW; DP Description:; - Positive components: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids; - Negative components: Refined Grains; Empty Calories (i.e., energy from solid fats, alcohol, and added sugars); Sodium; Outcomes:; PTB <37 GW | PTB; Multivariable Poisson Regression; RR (95% CI); Q1 vs Q4 (Ref): 1.11 (0.88, 1.42), p≥0.05; Q2 vs Q4 (Ref): 1.07 (0.85, 1.33), p≥0.05; Q3 vs Q4 (Ref): 0.99 (0.79, 1.23), p≥0.05 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Prepregnancy BMI, DM in current pregnancy; Other covariates: Chronic HTN, Mental health disorder, Marital status; Funding: NICHD; Clinical and Translational Science Institutes of Indiana University and UC Irvine; Summary: Alignment with the HEI-2010 was not associated with risk of PTB.
Yisahak, 2021^29^; PCS, United States, NICHD; Fetal Growth Studies-Singletons; Analytic N=1,948; - Age (y): Q1: ~26, Q4: ~30, p<0.001; - Race/Ethnicity (%): NHW: Q1: ~15, Q4: ~28; NHB: Q1: ~49, Q4: ~18; Hispanic: Q1: ~26, Q4: ~26; AAPI: Q1: ~10, Q4: ~29; - Socioeconomic position:; ○ Education <HS: Q1: ~15, Q4: ~9; HS or equivalent: Q1: ~27, Q4: ~13; Postgraduate: Q1: ~7, Q4: ~28, p<0.001; ○ Income ($) <30k: Q1: 47, Q4: 23; ≥100k: Q1: 11, Q4: 38, p<0.001; ○ Full-time school or work: Q1: 67, Q4: 71; ○ Insurance (private/managed care): Q1: 48, Q4: 72, p<0.001; - Pre-pregnancy BMI: Q1: ~26.1, Q4: 24.2, p<0.001; - Smoking (%):; ○ Smoking with obesity: n=17; ○ Smoking without obesity: 0.0 | AHEI-2010, aMed, DASH (quartiles of alignment); FFQ at: 8-13 GW; DP Description:; [underlined: AHEI-2010]; - Positive components: vegetables, fruits, whole grains, nuts and legumes, long-chain omega-3 fatty acids (EPA and DHA), PUFAs.; - Negative components: SSB red/processed meats, trans fat, sodium. Modified to eliminate alcohol component.; [underlined: aMed]; - Positive components: vegetables excluding potatoes, legumes, fruit, nuts, whole grains, fish, ratio of MUFA:SFA.; - Negative components: red and processed meats. Modified to eliminate alcohol component.; [underlined: DASH]; - Positive components: vegetables, fruits, whole grains, low-fat dairy, nuts, seeds, legumes.; - Negative components: red and processed meat, SSB, sodium.; Outcomes:; PTB <37 GW | PTB; Logistic regression; OR (95% CI); [underlined: AHEI-2010]; Q2 vs Q1 (Ref): 0.96 (0.52, 1.80); Q3 vs Q1 (Ref): 0.92 (0.48, 1.75); Q4 vs Q1 (Ref): 0.66 (0.32, 1.36); p trend: 0.48; [underlined: aMED]; Q2 vs Q1 (Ref): 0.69 (0.37, 1.28); Q3 vs Q1 (Ref): 0.61 (0.35, 1.05); Q4 vs Q1 (Ref): 0.49 (0.23, 1.05); p trend: 0.058; [underlined: DASH]; Q2 vs Q1 (Ref): 0.67 (0.36, 1.24); Q3 vs Q1 (Ref): 0.76 (0.44, 1.33); Q4 vs Q1 (Ref): 0.52 (0.26, 1.05); p trend: 0.093 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, income, current job/student status, insurance coverage, Pre-pregnancy BMI; Other covariates: height, marital status, study site, infant sex, total weekly physical activity, total daily energy intake; Funding: NICHD; American Recovery and Reinvestment Act; Summary: Alignment with AHEI-2010, aMED, and DASH were not associated with risk of PTB.
Zhu, 2021^30^; PCS, United States, PETALS; Exposure N=Q2: 624, Q3: 619, Q4: 627, Comparator N=Q1: 579; - Age (y, %): 18-24: 15.6, 25-29: 26.8, 30-34: 35.9, ≥35: 21.8; - Race/Ethnicity (%): Hispanic: 41.1; Asian/Pacific Islander: 23.8; White: 22.4; African American: 9.2; Other: 3.5; - Socioeconomic position:; ○ Education (%): ≤HS: 13.5; College graduate or above: 48.0; ○ Household income, annual (USD, %): <50k: 32.5, $50k-99,999: 31.9, ≥150k: 17.5; ○ Employment status (%): Fulltime: 64.4, Part-time: 17.6, Not employed/missing: 18.0; - Pre-pregnancy BMI: <18.5: 2.6, 25.0-29.9: 28.5, ≥30.0: 28.3; - Current HDP (%): Pre-existing HTN: 4.3; - Current DM (%): Pre-existing DM: 0; - Smoking (%):; ○ 1 mo before pregnancy: 5.3; ○ Since pregnancy: 0.4 | AHEI-P (quartiles of alignment); FFQ at: 10-13 GW; DP Description:; - Positive components: vegetables, whole fruit, whole grains, nuts and legumes, long-chain omega-3 fats (EPA+DHA), PUFA, calcium, folate, iron. Lower intake of SSB, red/processed meat, trans fat, sodium.; Outcomes:; PTB <37 GW | PTB; Poisson regression; RR (95% CI); Q2 vs Q1 (Ref): 0.68 (0.42, 1.12); Q3 vs Q1 (Ref): 0.61 (0.38, 1.00); Q4 vs Q1 (Ref): 0.50 (0.28, 0.89); p-trend: 0.037; Q4 vs Q1-Q3 (Ref): 0.68 (0.39, 0.99) | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, household income in model, Prepregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: history of PTB, PA, Perceived Stress Scale, perinatal depression, alcohol consumption before or during early pregnancy; Results remained robust in sensitivity analyses additionally adjusting for GDM and HDP.; Funding: NIEHS; NIH Office of the Director; NIDDK; NICHD; Community Health, Kaiser Permanente Northern California; NHLBI; Summary: Higher alignment with the AHEI-P was associated with lower risk of PTB.
Factor/Cluster Analysis
Bodnar, 2024^2^; PCS, United States, nuMoM2b; Exposure N=FVGP: 1,347; SS: 2,789; BGM: 1,742, Comparator N=2,381; For FSS; FVGP; SS; BGM; - Age (y, %):; ○ <25: 61, 8, 12, 48; ○ 25 to 34: 35, 74, 75, 45; ○ ≥35: 4, 18, 13, 7; - Race/Ethnicity (%):; ○ NHW: 48, 76, 84, 38; ○ NHB: 27, 3, 2, 11; ○ Hispanic: 16, 10, 8, 38; ○ Other: 9, 11, 6, 13; - Socioeconomic position: (% or median (IQR)); ○ Married: 33, 89, 85, 56; ○ Private Insurance: 48, 92, 91, 54; ○ Currently employed: 68, 91, 93, 71; ○ Acculturation:; US-born (self and parents): 80, 70, 82, 46;; US-born/immigrant parent: 14, 12, 11, 19;; Born outside US, immigrated at <18 y: 4, 9, 4, 18;; Born outside US, immigrated at ≥18 y: 2, 9, 3, 18;; ○ Education:; ≤HS: 38, 3, 4, 24; College graduate: 15, 38, 41, 24; Graduate degree: 6, 47, 35, 14; ○ Area Deprivation Index: 59 (55), 24 (34), 27 (33), 45 (62); ○ Percent of neighborhood in poverty: 18 (22), 11 (13), 10 (11), 17 (20); - Pre-pregnancy BMI: (%); ○ <18.5: 6, 4, 2, 5; ○ 18.5 to <25: 46, 69, 60, 54; ○ 25 to <30: 23, 18, 22, 23; ○ ≥30: 25, 10, 16, 18; - Current HDP (%): PE: Total 8.6, FSS: 11; FVGP: 6.4; SS: 7.8; BGM: 8.3; - Current DM (%): GDM: Total: 4.9, FSS: 5.5; FVGP: 4.1; SS: 4.7; BGM: 5.2; - Smoking (%): Preconception smoker: 30, 6, 14, 12 | Greater alignment with FVGP; SS; or BGM vs FSS DP; FFQ at: 6-13 GW; DP Description:; [underlined: High fruits, vegetables, whole grains, and plant proteins (FVGP)]; Higher intake of vegetable medley/other vegetables, apples/pears, tomatoes, lettuce, broccoli, bananas, spinach/greens, strawberries/other berries, avocado, citrus fruits, tofu/meat substitutes, peaches/plums/ apricots/nectarines, yogurt, salad dressing, peas/string beans, nuts/seeds/nut or seed mixed dishes, sweet potatoes, other fruit/fruit salad, melon, coffee; [underlined: Sandwiches and snacks (SS)]; Higher intake of coffee, alcoholic beverages, whole wheat bread, cold cuts, skim milk, diet soda/diet fruit drinks, pretzels/fat-free crackers/rice cakes, nuts/seeds/nut or seed mixed dishes, condiments, salad dressing, cream, unfried chicken or turkey/mixed dishes, crackers, reduced fat cheese, jam/jelly, white breads, sugars/honey, regular cheese, mayonnaise, nondairy creamer/cream substitutes; [underlined: Beverages, refined grains, and mixed dishes (BGM)]; Higher intake of reduced fat milk, 100% juice (not orange or grapefruit), rice/rice mixed dishes, 100% orange or grapefruit juice, Mexican mixed dishes, dried beans, soup, liver/other organ meats, whole milk, cold cereals, hot cereal, oils, vegetable juice, other white potatoes, vegetable mixed dishes, other meat/other meat mixed dishes, syrups/toppings, eggs/egg mixed dishes, pancakes/waffles/French toast/Pop Tarts, coleslaw; [underlined: High fat, sugar, and sodium (FSS)]; Higher intake of regular soda, fried chicken or fried turkey, fried white potatoes, burgers, sausage/franks/bacon/ribs, fruit drinks, chips/popcorn/other salty snacks, candy, pizza, grain desserts, other meat/other meat mixed dishes, white yeast breads, pancakes/waffles/French toast/Pop Tarts, dairy desserts, margarine, quick breads, beef/beef mixed dishes, crackers, other white potatoes, mayonnaise; HEI-2015 score and nearly all components of Healthy US-Style Eating Pattern were highest in the High fruits, vegetables, whole grains, and plant proteins DP and lowest in the High fat, sugar, and sodium DP. There were no meaningful differences in dairy, total protein foods, meats, poultry, and eggs, or seafood intake by DP.; Outcomes:; PTB: <37 GW; Early PTB: <334 GW; Late PTB: ≥34-<337 GW; Spontaneous PTB: occurring subsequent to spontaneous onset of labor or premature rupture of the membranes, regardless of subsequent labor augmentation or cesarean delivery | PTB; Targeted minimum loss-based estimation Adjusted number of excess cases per 100 pregnancies (95% CI); FVGP: 0.39 (−1.9, 2.6); SS: 0.91 (−0.87, 2.7); BGM: 1.2 (−1.0, 3.5); FSS: 0 (Ref); Early PTB; FVGP: 0.89 (−0.62, 2.4); SS: 0.20 (−0.80, 1.2); BGM: 0.70 (−0.52, 1.9); FSS: 0 (Ref); Late PTB; FVGP: −0.66 (−2.4, 1.1); SS: 0.56 (−0.98, 2.1); BGM: 0.50 (−1.5, 2.5); FSS: 0 (Ref); Spontaneous PTB; FVGP: 0.25 (−1.5, 2.0); SS: 0.74 (−0.61, 2.1); BGM: 0.67 (−0.99, 2.3); FSS: 0 (Ref) | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-Pregnancy BMI, DM in current pregnancy; Other covariates: Other sociodemographic factors (marital status, whether the pregnancy was planned), other medical factors (gravidity, nausea and vomiting, season of conception and assisted reproductive technologies), other behaviors (binge drinking, prenatal vitamin use, PA), psychosocial factors (depressive symptoms, anxiety, perceived stress, resilience, health literacy, and sleep satisfaction).; Funding: NICHD; Indiana Univ; Univ of California Irvine; Summary: High alignment with the FVGP, SS, or BGM DP versus high alignment with the FSS DP was not associated with risk of PTB, Early PTB, Late PTB, or Spontaneous PTB.
Chia, 2016^3^; PCS, Singapore, GUSTO; Analytic N=923; By VFR score (Quintile 1; 3; 5); - Age (y): 28.2±5.1; 29.8±5.0; 32.4±4.8; - Race/Ethnicity (%):; ○ Chinese: 35; 50; 76; ○ Malayan: 56; 33; 5; ○ Indian: 9; 17; 20; - Socioeconomic position:; ○ Education:; None, primary, or secondary: 41; 33; 21; Postsecondary: 40; 38; 31; University: 19; 28; 48; - Pre-pregnancy BMI: 22.5±4.7; 22.7±4.7; 22.1±3.6; - Current HDP (%): 6.0; 4.3; 3.3; - Current DM (%): No serious health conditions such as T1DM;; ○ GDM: 12; 12; 26; - Smoking (%): Current Smoker: 7.1; 2.1; 0.5 | VFR, SfN, and PCP DP (higher vs lower alignment); 24 HR, 3-d food diary at: 26-28 GW; DP Description:; [underlined: Vegetable, fruit, and white rice (VFR) DP]; - Higher intakes of vegetables, fruits, plain white rice, whole-grain bread, fish, and nuts and seeds, and; - Lower intakes of fried potatoes, burgers, carbonated and sweetened drinks, and flavored rice; [underlined: Seafood and noodle (SfN) DP]; - Higher intakes of soup, seafood, fish and seafood products, noodles (flavored and in soup), and low-fat red meat; - Lower intakes of legumes, ethnic bread, white rice, and curry-based gravies; [underlined: Pasta, cheese, and processed meat (PCP) DP]; - Higher intake of pasta-, tomato-, and cream-based gravies, cheese, and processed meat; Outcomes:; PTB (All <37 GW, Spontaneous, Induced) | All PTB; Logistic Regression; OR (95% CI); [underlined: VFR]: 0.67 (0.50, 0.91), p<0.05; [underlined: SfN]: 1.27 (0.93, 1.74); [underlined: PCP]: 0.79 (0.55, 1.12); Spontaneous PTB; Logistic Regression; OR (95% CI); [underlined: VFR]: 0.55 (0.37, 0.82); [underlined: SfN]: 1.20 (0.78, 1.83); [underlined: PCP]: 0.71 (0.42, 1.19); Induced PTB; Logistic Regression; OR (95% CI); [underlined: VFR]: 1.18 (0.69, 2.03); [underlined: SfN]: 1.21 (0.67, 2.20); [underlined: PCP]: 0.50 (0.18, 1.42); Subgroup analysis with DP from 3d food records (n=212) showed no statistically significant association between VFR or SfN and PTB. | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-Pregnancy BMI, DM in current pregnancy; Other covariates: Infant sex, and maternal total energy intake, weight gain until 26–28 wk of gestation, height, alcohol use, and other dietary patterns; Funding: Singapore National Research Foundation; Agency for Science, Technology, and Research; Nestec; Summary: Greater alignment with the vegetable, fruit, and white rice DP was associated with a lower risk of all PTB and spontaneous PTB, but not induced PTB.; There was no association between the seafood and noodle DP or the pasta, cheese, and processed meat DP and all PTB, spontaneous PTB, or induced PTB.
de Seymour, 2022^5^; PCS, China, CLIMB; Analytic N=962; - Age (y): Median (IQR): 28 (26, 31); - Race/Ethnicity (%): Han ethnicity: 97.9; - Socioeconomic position:; ○ Tertiary level education (%): 63.1; ○ Household income (%): <7k yuan/mo: 19.5; >10k yuan/mo: 44.5; - Baseline BMI: Median (IQR): 21.0 (19.4, 22.9); - Current HDP (%): PE: 1.7; - Current DM (%): GDM: 27.7; - Previous pregnancy complication resulting in delivery <32 GW (%): 0.0 | FPV DP & PSO DP (continuous alignment); FFQ at: 11-14 GW; DP Description:; [underlined: Fish, poultry and vegetables (FPV) DP]:; Higher in fish; poultry; legumes and bean products; green leafy vegetables; root vegetables; other vegetables; seafood; fruits; eggs; organ meats; beverages; bread; dairy; soup; nuts; [underlined: Pasta, sweetened beverages, oils and condiments (PSO) DP]:; Higher in pasta; sweetened beverages; oils and condiments; fast food; Outcomes:; PTB | PTB; Binomial logistic regression; OR (95% CI); [underlined: FPV DP]: 1.130 (0.818, 1.561), p=0.458; [underlined: PSO DP]: 1.165 (0.877, 1.546), p=0.291 | Key confounders accounted for:; Race and/or ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: CLIMB treatment group; Offspring sex; total energy intake; Other DP; Funding: Joint Health Research Council New Zealand–National Science Foundation of China; Lottery Health New Zealand; Fonterra Co-operative Group Ltd., New Zealand; New Zealand Ministry for Primary Industries; Summary: Alignment with the FPV DP and PSO DP was not associated with risk of PTB.
Englund-Ögge, 2014^6^; PCS, Norway, MoBa; Analytic N=66,000; - Age (y): Mean: 30.1 (%) <20: 1.0; 20-29: 44.5; 30-39: 52.5; ≥40: 2.0; - Socioeconomic position:; ○ Education (y, %): <13: 31.0; 13-16: 41.6; ≥17: 25.3; ○ Household income (%): Both partners <300k NOK: 27.8; Either participant or partner ≥300k NOK: 41.0; Both participant and partner ≥300k NOK: 28.3; - Pre-pregnancy BMI: (%) <18.5: 3.1; 18.5-24.9: 64.7; 25-29.9: 20.8; ≥30: 8.8; - Current DM (%): 0.0; - Smoking (%): During pregnancy: Occasional: 2.6; Daily: 5.4 | Prudent DP, Western DP, and Traditional DP (tertiles of alignment); FFQ at: 17-22 GW; DP Description:; [underlined: Prudent pattern]; - Higher intake of raw and cooked vegetables, salad, onion/leek/garlic, fruit and berries, nuts, vegetables oils, water as beverage, whole grain cereals, poultry, and fibre rich bread; - Lower intake of processed meat products (hot dogs, hamburgers, and so on), white bread, and pizza/tacos; [underlined: Western pattern]; - Higher intake of salty snacks, chocolate and sweets, cakes, French fries, white bread, ketchup, sugar sweetened drinks, processed meat products, and pasta; - Lower intake of lean fish and fibre rich bread; [underlined: Traditional pattern]; - Higher intake of boiled potatoes, fish products, gravy, lean fish, margarine, rice pudding, low fat milk, and cooked vegetables; - Lower intake of poultry and pizza/tacos; Outcomes:; PTB (includes spontaneous and iatrogenic): <37 GW; Late preterm: 34-<37 GW; Moderately preterm: 32-<34 GW; Early preterm: 22-<32 GW | Preterm; Cox Regression; HR (95% CI); [underlined: Prudent DP]; T2 vs T1 (Ref): 0.94 (0.86, 1.02); T3 vs T1 (Ref): 0.88 (0.80, 0.97); p-trend=0.006; [underlined: Western DP]; T2 vs T1 (Ref): 1.04 (0.95, 1.13); T3 vs T1 (Ref): 1.02 (0.92, 1.13); p-trend=0.695; [underlined: Traditional DP]; T2 vs T1 (Ref): 0.98 (0.90, 1.06); T3 vs T1 (Ref): 0.91 (0.83, 0.99); p-trend=0.043; Spontaneous preterm; Cox Regression; HR (95% CI); [underlined: Prudent DP]; T2 vs T1 (Ref): 0.90 (0.81, 1.01); T3 vs T1 (Ref): 0.85 (0.75, 0.96); p-trend=0.008; [underlined: Western DP]; T2 vs T1 (Ref): 1.10 (0.98, 1.23); T3 vs T1 (Ref): 1.04 (0.91, 1.19); p-trend=0.504; [underlined: Traditional DP]; T2 vs T1 (Ref): 0.96 (0.86, 1.07); T3 vs T1 (Ref): 0.96 (0.85, 1.09); p-trend=0.512; Iatrogenic preterm; Cox Regression; HR (95% CI); [underlined: Prudent DP]; T2 vs T1 (Ref): 1.00 (0.88, 1.15); T3 vs T1 (Ref): 0.93 (0.80, 1.08); p-trend=0.328; [underlined: Western DP]; T2 vs T1 (Ref): 1.00 (0.87, 1.15); T3 vs T1 (Ref): 1.05 (0.90, 1.23); p-trend: 0.548; [underlined: Traditional DP]; T2 vs T1 (Ref): 1.01 (0.89, 1.15); T3 vs T1 (Ref): 0.85 (0.74, 0.99); p-trend=0.042; Late preterm; Cox Regression; HR (95% CI); [underlined: Prudent DP]; T2 vs T1 (Ref): 0.91 (0.82, 0.99); T3 vs T1 (Ref): 0.86 (0.78, 0.96); p-trend=0.007; [underlined: Western DP]; T2 vs T1 (Ref): 1.06 (0.96, 1.17); T3 vs T1 (Ref): 1.06 (0.94, 1.19); p-trend=0.323; [underlined: Traditional DP]; T2 vs T1 (Ref): 0.98 (0.89, 1.08); T3 vs T1 (Ref): 0.89 (0.80, 0.99); p-trend=0.032; Moderately preterm; Cox Regression; HR (95% CI); [underlined: Prudent DP]; T2 vs T1 (Ref): 0.94 (0.75, 1.17); T3 vs T1 (Ref): 0.91 (0.71, 1.17); p-trend=0.485; [underlined: Western DP]; T2 vs T1 (Ref): 0.81 (0.64, 1.02); T3 vs T1 (Ref): 0.79 (0.60, 1.04); p-trend=0.074; [underlined: Traditional DP]; T2 vs T1 (Ref): 1.02 (0.81, 1.28); T3 vs T1 (Ref): 1.02 (0.79, 1.32); p-trend=0.869; Early preterm; Cox Regression; HR (95% CI); [underlined: Prudent DP]; T2: 1.10 (0.88, 1.38); T3: 0.92 (0.71, 1.19); p-trend=0.521; [underlined: Western DP]; T2 vs T1 (Ref): 1.21 (0.95, 1.53); T3 vs T1 (Ref): 1.09 (0.82, 1.44); p-trend=0.541; [underlined: Traditional DP]; T2 vs T1 (Ref): 0.93 (0.74, 1.16); T3 vs T1 (Ref): 0.90 (0.69, 1.15); p-trend=0.414 | Key confounders accounted for:; Parity, Smoking, Age, Socioeconomic position, HH income in model, Pre-Pregnancy BMI, DM in current pregnancy; Other covariates: Maternal height, total energy intake, marital status, previous preterm delivery, and other dietary patterns; Funding: Freemasons Directorate board for Children, the Adlerbertska Foundation, the Hjalmar Svensson Foundation, the Norwegian Research Council, the Jane and Dan Olsson Foundation, the Swedish Medical Society, and Swedish government grants to researchers in public health service; MoBa was also supported by the Norwegian Ministry of Health and the Ministry of Education and Research, NIEHS, NINDS, and the Norwegian Research Council/FUGE; Summary: Higher alignment with the Prudent DP was associated with a reduced risk of PTB as well as late PTB and spontaneous PTB. Higher alignment with the Traditional DP was associated with a reduced risk of PTB as well as late PTB and iatrogenic PTB. The Western dietary pattern was not associated with PTB.
Grieger, 2014^8^; PCS, Australia, Lyell McEwin Hospital; Analytic N=309; - Age (y): 26.6±5.4; - Race/Ethnicity (%): Caucasian: 89; Non-Caucasian: 11; - Socioeconomic position: Socioeconomic status (%) 5 (highest): 5; 4: 5; 3: 3; 2: 30; 1 (lowest): 52; - Pre-pregnancy BMI: 27.6±6.6; - Smoking (n, %): Never/former 211 (68); Quit in pregnancy/current 98 (32) | High-protein/fruit; High-fat/sugar/takeaway; Vegetarian-type DP (continuous, per SD of alignment); FFQ at: 13 GW; DP Description:; [underlined: High-protein/fruit]; Higher intake of fish, meat, chicken, fruit, whole grains; [underlined: High-fat/sugar/takeaway]; Higher intake of takeaway foods, potato chips, refined grains, added sugar; [underlined: Vegetarian-type]; Higher intake of vegetables, whole grains, legumes; Outcomes:; PTB <37 GW | PTB; Binary logistic regression; OR (95% CI), per SD increase in DP alignment; [underlined: High protein/fruit]: 0.31 (0.13, 0.72), p=0.007; [underlined: High fat/sugar/take-away]: 1.54 (1.10, 2.15), p=0.011; [underlined: Vegetarian type]: 1.08 (0.74, 1.57), p=0.69 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-Pregnancy BMI; Other covariates: Asthma status; Funding: National Health and Medical Research Council Senior Research Fellowship; Summary: Alignment with the High protein/fruit DP was associated with a reduced risk of PTB, and alignment with the High-fat/sugar/takeaway DP was associated with an increased risk of PTB. Alignment with the Vegetarian DP was not associated with risk of PTB.
Hu, 2023^12^; PCS, China, China Medical University birth cohort; Analytic N=1,500; - Age (y): >35 (%): No PTB: 20.4; PTB: 24.9; - Race/Ethnicity (%): Chinese Han: No PTB: 92.8; PTB: 90.5; Other: No PTB: 7.2; PTB: 9.5; - Socioeconomic position:; ○ Education (%): ≤HS: No PTB: 12.1; PTB: 12.9; ○ Household income (%): <50k CNY/y: No PTB: 39.1; PTB: 46.7, p=0.07; - Pre-pregnancy BMI: (%) <18.5: No PTB: 12.9; PTB: 13.2 ≥24: No PTB: 28.1; PTB: 37.7, p=0.03; - Smoking (%): No PTB: 97.9; PTB: 97.2 | Fish-seafood DP, Dairy-egg DP, Meat-staple DP, Fruit–vegetable DP (tertiles of alignment); FFQ at: TM1, TM2, and TM3; DP Description:; [underlined: Fish-seafood DP]; Higher intake of freshwater fish, marine fish, shrimps, crabs, mussels, seaweed, poultry, and organ Fish-seafood DP: Higher intake of freshwater fish, marine fish, shrimps, crabs, mussels, seaweed, poultry, and organ meats in TM1, TM2, & TM3; Additionally in TM1 and TM3 only: beef and lamb; Additionally in TM3 only: tubers; [underlined: Dairy-egg DP]; Higher intake of dairy products, milk, eggs, egg products, beans, bean products, and nuts in TM1, TM2, & TM3; [underlined: Meat-staple DP]; Higher intake of pork, poultry, beef, lamb, organ meats, tubers, and rice in TM2 & TM3; Also in TM3: wheat flour and products; [underlined: Fruit–vegetable DP]; Higher intake of fruits, vegetables, beans, and bean products in TM1; Outcomes:; PTB: <37 GW; Spontaneous PTB (SPTB): PTB either preceded by preterm labor or premature rupture of the membranes Iatrogenic PTB (IPTB): Induction of labor or cesarean section without labor <37 GW based on the health of the child or birthing parent | PTB <37 GW; Multinomial logistic regression; OR (95% CI); [underlined: TM1 Fish-seafood DP]; T2 vs T1 (Ref): 2.07 (1.30, 3.29), p<0.05; T3 vs T1 (Ref): 2.29 (1.32, 3.96), p<0.05; p for trend=0.018; [underlined: TM1 Dairy-egg DP]; T2 vs T1 (Ref): 0.65 (0.41, 1.02), p=NS; T3 vs T1 (Ref): 0.72 (0.43, 1.22), p=NS; p for trend=0.533; [underlined: TM1 Fruit–vegetable DP]; T2 vs T1 (Ref): 1.15 (0.76, 1.76), p=NS; T3 vs T1 (Ref): 1.17 (0.72, 1.88), p=NS; p for trend=0.576; [underlined: TM2 Fish-seafood DP]; T2 vs T1 (Ref): 0.57 (0.34, 0.96), p<0.05; T3 vs T1 (Ref): 0.49 (0.25, 0.93), p<0.05; p for trend=0.065; [underlined: TM2 Meat-staple DP]; T2 vs T1 (Ref): 1.19 (0.73, 1.95), p=NS; T3 vs T1 (Ref): 1.32 (0.68, 2.55), p=NS; p for trend=0.500; [underlined: TM2 Dairy-egg DP]; T2 vs T1 (Ref): 1.36 (0.83, 2.21), p=NS; T3 vs T1 (Ref): 1.99 (1.11, 3.60), p<0.05; p for trend=0.032; [underlined: TM3 Fish-seafood DP]; All participants; T2 vs T1 (Ref): 0.94 (0.52, 1.72), p=NS; T3 vs T1 (Ref): 0.93 (0.43, 2.00), p=NS; p for trend=0.824; [underlined: TM3 Meat-staple DP]; T2 vs T1 (Ref): 1.04 (0.58, 1.84), p=NS; T3 vs T1 (Ref): 1.28 (0.60, 2.73), p=NS; p for trend=0.440; [underlined: TM3 Dairy-egg DP]; T2 vs T1 (Ref): 2.28 (1.23, 4.22), p<0.05; T3 vs T1 (Ref): 2.44 (1.15, 5.18), p<0.05; p for trend=0.040; [underlined: TM1, TM2, and TM3 Fish-seafood DP]; GEE Model; OR (95% CI); All participants:; T2 vs T1 (Ref): 1.12 (0.83, 1.53), p=NS; T3 vs T1 (Ref): 1.13 (0.76, 1.69), p=NS; p for trend=0.611; Subgroup analysis by pre-pregnancy BMI, p for interaction=0.139; Pre-pregnancy BMI <18.5:; T2 vs T1 (Ref): 1.61 (0.77, 3.36), p=NS; T3 vs T1 (Ref): 1.95 (0.78, 4.85), p=NS; p for trend=0.171; Pre-pregnancy BMI 18.5-<24:; T2 vs T1 (Ref): 1.07 (0.68, 1.68), p=NS; T3 vs T1 (Ref): 1.05 (0.59, 1.85), p=NS; p for trend= 0.900; Pre-pregnancy BMI ≥24:; T2 vs T1 (Ref): 1.00 (0.60, 1.67), p=NS; T3 vs T1 (Ref): 0.94 (0.47, 1.90), p=NS; p for trend=0.832; Subgroup analysis by Child Sex, p for interaction=0.022; Male Child Sex:; T2 vs T1 (Ref): 0.91 (0.62, 1.33), p=NS; T3 vs T1 (Ref): 0.76 (0.46, 1.27), p=NS; p for trend=0.322; Female Child Sex:; T2 vs T1 (Ref): 1.51 (0.91, 2.52), p=NS; T3 vs T1 (Ref): 1.95 (1.04, 3.67), p<0.05; p for trend=0.045; [underlined: TM1, TM2, and TM3 Dairy-egg DP]; GEE Model; OR (95% CI); All participants:; T2 vs T1 (Ref): 1.17 (0.85, 1.59), p=NS; T3 vs T1 (Ref): 1.46 (0.96, 2.22), p=NS; p for trend=0.047; Subgroup analysis by pre-pregnancy BMI, p for interaction=0.015; Pre-pregnancy BMI <18.5:; T2 vs T1 (Ref): 0.85 (0.42, 1.71), p=NS; T3 vs T1 (Ref): 0.53 (0.22, 1.30), p=NS; p for trend=0.203; Pre-pregnancy BMI 18.5-<24:; T2 vs T1 (Ref): 1.11 (0.72, 1.72), p=NS; T3 vs T1 (Ref): 1.44 (0.81, 2.56), p=NS; p for trend=0.157; Pre-pregnancy BMI ≥24:; T2 vs T1 (Ref): 1.44 (0.83, 2.50), p=NS; T3 vs T1 (Ref): 2.54 (1.22, 5.29), p<0.05; p for trend=0.009; Subgroup analysis by Child Sex, p for interaction=0.212; Male Child Sex:; T2 vs T1 (Ref): 1.62 (1.09, 2.41), p<0.05; T3 vs T1 (Ref): 1.80 (1.03, 3.14), p<0.05; p for trend=0.033; Female Child Sex:; T2 vs T1 (Ref): 0.73 (0.45, 1.20), p=NS; T3 vs T1 (Ref): 1.10 (0.60, 2.01), p=NS; p for trend=0.529; SPTB; Multinomial logistic regression; OR (95% CI); [underlined: TM1 Fish-seafood DP]; T2 vs T1 (Ref): 2.07 (0.87, 4.93), p=NS; T3 vs T1 (Ref): 2.39 (0.83, 6.88), p=NS; p for trend=0.183; [underlined: TM1 Dairy-egg DP]; T2 vs T1 (Ref): 0.45 (0.19, 1.09), p=NS; T3 vs T1 (Ref): 0.54 (0.20, 1.47), p=NS; p for trend=0.306; [underlined: TM1 Fruit–vegetable DP]; T2 vs T1 (Ref): 0.91 (0.40, 2.09), p=NS; T3 vs T1 (Ref): 1.22 (0.49, 3.05), p=NS; p for trend=0.638; [underlined: TM2 Fish-seafood DP]; T2 vs T1 (Ref): 0.40 (0.14, 1.10), p=NS; T3 vs T1 (Ref): 0.53 (0.15, 1.87), p=NS; p for trend=0.505; [underlined: TM2 Meat-staple DP]; T2 vs T1 (Ref): 0.87 (0.34, 2.23), p=NS; T3 vs T1 (Ref): 0.91 (0.24, 3.42), p=NS; p for trend=0.820; [underlined: TM2 Dairy-egg DP]; T2 vs T1 (Ref): 1.21 (0.49, 2.99), p=NS; T3 vs T1 (Ref): 1.54 (0.48, 4.94), p=NS; p for trend=0.628; [underlined: TM3 Fish-seafood DP]; T2 vs T1 (Ref): 1.52 (0.42, 5.48), p=NS; T3 vs T1 (Ref): 0.59 (0.11, 3.17), p=NS; p for trend=0.345; [underlined: TM3 Meat-staple DP]; T2 vs T1 (Ref): 0.70 (0.20, 2.50), p=NS; T3 vs T1 (Ref): 2.11 (0.46, 9.75), p=NS; p for trend=0.177; [underlined: TM3 Dairy-egg DP]; T2 vs T1 (Ref): 0.93 (0.27, 3.16), p=NS; T3 vs T1 (Ref): 1.53 (0.36, 6.56), p=NS; p for trend=0.459; IPTB; Multinomial logistic regression; OR (95% CI); [underlined: TM1 Fish-seafood DP]; T2 vs T1 (Ref): 2.06 (1.21, 3.52), p<0.05; T3 vs T1 (Ref): 2.26 (1.21, 4.20), p<0.05; p for trend=0.041; [underlined: TM1 Dairy-egg DP]; T2 vs T1 (Ref): 0.73 (0.43, 1.23), p=NS; T3 vs T1 (Ref): 0.80 (0.44, 1.45), p=NS; p for trend=0.865; [underlined: TM1 Fruit–vegetable DP]; T2 vs T1 (Ref): 1.25 (0.78, 2.01), p=NS; T3 vs T1 (Ref): 1.17 (0.68, 2.01), p=NS; p for trend=0.665; [underlined: TM2 Fish-seafood DP]; T2 vs T1 (Ref): 0.64 (0.36, 1.15), p=NS; T3 vs T1 (Ref): 0.48 (0.23, 1.00), p=NS; p for trend= 0.070; [underlined: TM2 Meat-staple DP]; T2 vs T1 (Ref): 1.34 (0.76, 2.35), p=NS; T3 vs T1 (Ref): 1.50 (0.71, 3.16), p=NS; p for trend=0.351; [underlined: TM2 Dairy-egg DP]; T2 vs T1 (Ref): 1.44 (0.82, 2.51), p<0.05; T3 vs T1 (Ref): 2.17 (1.12, 4.22), p<0.05; p for trend=0.024; [underlined: TM3 Fish-seafood DP]; T2 vs T1 (Ref): 0.84 (0.43, 1.63), p=NS; T3 vs T1 (Ref): 1.05 (0.45, 2.44), p=NS; p for trend=0.834; [underlined: TM3 Meat-staple DP]; T2 vs T1 (Ref): 1.13 (0.59, 2.15), p=NS; T3 vs T1 (Ref): 1.10 (0.47, 2.57), p=NS; p for trend=0.835; [underlined: TM3 Dairy-egg DP]; T2 vs T1 (Ref): 3.04 (1.49, 6.19), p<0.05; T3 vs T1 (Ref): 2.95 (1.24, 7.03), p<0.05; p for trend=0.045 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI; Other covariates: Physical activity; total energy intake; Child sex; Other DP during same trimester; DP in previous trimester; Funding: National Natural Science Foundation of China Grant; Summary: In all participants, greater alignment with the TM1 Fish-seafood DP was associated with higher risk of overall PTB and IPTB, but not SPTB. In all participants, greater alignment with the TM2 Fish-seafood DP was associated with lower risk of overall PTB compared to lower alignment, although the trend was not statistically significant. Greater alignment with the TM2 Fish-seafood DP was not associated with risk of SPTB, but the association trended toward statistical significance for IPTB. In all participants, alignment with the TM3 Fish-seafood DP was not associated with risk of overall PTB, IPTB, or SPTB.; In all participants, greater alignment with the Fish-seafood DP over all three trimesters was not associated with risk of overall PTB. Subgroup analyses by pre-pregnancy BMI did not substantively change these results. However, subgroup analyses by child sex indicated that greater alignment with the Fish-seafood DP over all three trimesters was associated with higher risk of overall PTB when the child was female, but not when the child was male.; In all participants, greater alignment with the TM2 and TM3 Dairy-egg DP was associated with higher risk of overall PTB and IPTB, but not SPTB. Alignment with the TM1 Dairy-egg DP was not associated with risk of overall PTB, IPTB, or SPTB.; In all participants, greater alignment with the Diary-egg DP over all three trimesters was associated with higher risk of overall PTB. Subgroup analyses by pre-pregnancy BMI indicated that greater alignment with the Dairy-egg DP over all three trimesters was associated with higher risk of overall PTB in participants with pre-pregnancy BMI ≥24, but not in participants with pre-pregnancy BMI <18.5 or 18.5-<24. Subgroup analyses by child sex indicated that greater alignment with the Dairy-egg DP over all three trimesters was associated with higher risk of overall PTB when the child was male, but not when the child was female.; In all participants, greater alignment with the TM1 Fruit-vegetable DP and both the TM2 and TM3 Meat-staple DP were not associated with risk of overall PTB, IPTB, or SPTB.
Lu, 2018^15^; PCS, China, BIGCS; Analytic N=7,352; - Age (y): 29.1±3.3, p=0.002 between DP; - Race/Ethnicity (%): Chinese nationality: 100; - Socioeconomic position:; - Education (%): ≤HS: 8.5; Vocational/technical college: 24.6; Undergraduate: 54.8; Postgraduate: 12.1, p<0.001 between DP; - Income (yuan/mo, %): ≤1,500: 9.4; 1501-4500: 30.9; ≥9,001: 15.8; Missing: 2.3, p<0.001 between DP; - Pre-pregnancy BMI: (%): <18.5: 24.5; ≥24: 11.5; - Current HDP (%): Chronic HTN: 0.0; - Current DM (%): T1 or T2 DM: 0.0; - Smoking (%): Passive smoking: 30.2, p<0.001 between DP | Varied DP; Milk DP; Cereals, eggs, and Cantonese soups DP; Meats DP; & Fruits, nuts, and Cantonese desserts DP vs Vegetables DP; Rich DP, Milk-S DP, Fruits DP, Meats-S DP, Moderate DP, & Prudent DP (each DP vs other DPs); FFQ at: 24-27 GW; DP Description:; [underlined: Varied DP]: Higher intakes of mixed foods, including noodles, bread, root vegetables, melon vegetables, mushrooms, sea vegetables, bean vegetables, processed vegetables, poultry, animal organ meat, fish, other seafood, bean products, yoghurt, sweet beverages, puffed food, confectioneries, and snacks; [underlined: Milk DP]: Higher intakes of milk products (including fresh milk, pasteurized milk, milk powder, and formula for pregnant women) and lower intakes of whole vegetables; [underlined: Cereals, eggs, and Cantonese soups DP]: Higher intakes of rice, pasta, porridge, eggs, and Cantonese soups; [underlined: Meats DP]: Higher intakes of red and processed meat; [underlined: Fruits, nuts, and Cantonese desserts DP: Higher] intakes of fruits, nuts, and Cantonese desserts; Vegetables DP: Higher intakes of leafy and cruciferous vegetables; [underlined: Rich DP]: Higher intakes of grains, vegetables, poultry, animal organ meat, eggs, fish, other seafood, bean products, nuts, yoghurt, confectioneries, and snacks; [underlined: Milk-S DP]: Higher intake of milk; [underlined: Fruits DP]: Higher intakes of fruits, sweet beverages, Cantonese desserts, and puffed food; [underlined: Meats-S DP]: Higher intakes of red meat, processed meat, and Cantonese soups; [underlined: Prudent DP]: Lower intakes of all food groups, including cereals, vegetables and fruits, meats, eggs, fish, other seafood, bean products, nuts, milk, yoghurt, sweet beverages, Cantonese desserts, Cantonese soups, puffed food, confectioneries, snacks; Outcomes:; PTB: <37 GW; Spontaneous PTB (SPTB): Spontaneous onset of PTB Iatrogenic PTB (IPTB): Induced or Caesarean delivery based on parental or fetal indications; Late PTB: 34-<37 GW; Early/Moderate PTB: <34 GW | PTB; Logistic regression; OR (95% CI); [underlined: Varied DP] (n=1742) vs Vegetables DP (Ref, n=1442): 1.27 (0.90, 1.80), p=NS; [underlined: Milk DP] (n=1090) vs Vegetables DP (Ref): 1.59 (1.11, 2.29), p<0.05; [underlined: Cereals, eggs, and Cantonese soups DP] (n=1078) vs Vegetables DP (Ref): 1.31 (0.89, 1.92), p=NS; [underlined: Meats DP] (n=1125) vs Vegetables DP (Ref): 1.01 (0.67, 1.51), p=NS; [underlined: Fruits, nuts, and Cantonese desserts DP] (n=875) vs Vegetables DP (Ref): 1.30 (0.87, 1.96), p=NS; [underlined: Rich DP] (n=381): 0.68 (0.39, 1.20), p=NS; [underlined: Milk-S DP] (n=864): 1.30 (0.96, 1.77), p=NS; [underlined: Fruits DP] (n=930): 1.10 (0.80, 1.51), p=NS; [underlined: Meats-S DP] (n=975): 0.78 (0.55, 1.11), p=NS; [underlined: Prudent DP] (n=2467): 1.02 (0.81, 1.28), p=NS; SPTB; Logistic regression; OR (95% CI); [underlined: Varied DP] vs Vegetables DP (Ref): 1.29 (0.86, 1.92), p=NS; [underlined: Milk DP] vs Vegetables DP (Ref): 1.73 (1.14, 2.62), p<0.05; [underlined: Cereals, eggs, and Cantonese soups DP] vs Vegetables DP (Ref): 1.30 (0.83, 2.03), p=NS; [underlined: Meats DP] vs Vegetables DP (Ref): 1.00 (0.63, 1.60), p=NS; [underlined: Fruits, nuts, and Cantonese desserts DP] vs Vegetables DP (Ref): 1.41 (0.89, 2.24), p=NS; [underlined: Rich DP]: 0.41 (0.18, 0.93), p<0.05; [underlined: Milk-S DP]: 1.44 (1.02, 2.02), p<0.05; [underlined: Fruits DP]: 1.13 (0.78, 1.62), p=NS; [underlined: Meats-S DP]: 0.73 (0.48, 1.10), p=NS; [underlined: Prudent DP]: 1.01 (0.77, 1.31), p=NS; IPTB; Logistic regression; OR (95% CI); [underlined: Varied DP] vs Vegetables DP (Ref): 0.79 (0.38, 1.61), p=NS; [underlined: Milk DP] vs Vegetables DP (Ref): 0.79 (0.34, 1.74), p=NS; [underlined: Cereals, eggs, and Cantonese soups DP] vs Vegetables DP (Ref): 0.90 (0.40, 1.94), p=NS; [underlined: Meats DP] vs Vegetables DP (Ref): 0.46 (0.16, 1.14), p=NS; [underlined: Fruits, nuts, and Cantonese desserts DP] vs Vegetables DP (Ref): 0.87 (0.36, 1.97), p=NS; [underlined: Rich DP]: 2.08 (0.83, 4.42), p=NS; [underlined: Milk-S DP]: 1.09 (0.48, 2.14), p=NS; [underlined: Fruits DP]: 0.93 (0.40, 1.90), p=NS; [underlined: Meats-S DP]: 0.63 (0.23, 1.40), p=NS; [underlined: Prudent DP]: 0.98 (0.57, 1.65), p=NS; Late PTB; Logistic regression; OR (95% CI); [underlined: Varied DP] vs Vegetables DP (Ref): 1.46 (0.99, 2.15), p=NS; [underlined: Milk DP] vs Vegetables DP (Ref): 1.73 (1.08, 2.62), p<0.05; [underlined: Cereals, eggs, and Cantonese soups DP] vs Vegetables DP (Ref): 1.54 (1.01, 2.35), p<0.05; [underlined: Meats DP] vs Vegetables DP (Ref): 1.11 (0.73, 1.79), p=NS; [underlined: Fruits, nuts, and Cantonese desserts DP] vs Vegetables DP (Ref): 1.61 (1.04, 2.50), p<0.05; [underlined: Rich DP]: 0.50 (0.25, 1.02), p=NS; [underlined: Milk-S DP]: 1.23 (0.87, 1.72), p=NS; [underlined: Fruits DP]: 1.19 (0.85, 1.67), p=NS; [underlined: Meats-S DP]: 0.72 (0.49, 1.07), p=NS; [underlined: Prudent DP]: 1.08 (0.85, 1.39), p=NS; Early/Moderate DP; Logistic regression; OR (95% CI); [underlined: Varied DP] vs Vegetables DP (Ref): 0.73 (0.34, 1.55), p=NS; [underlined: Milk DP] vs Vegetables DP (Ref): 1.19 (0.56, 2.50), p=NS; [underlined: Cereals, eggs, and Cantonese soups DP] vs Vegetables DP (Ref): 0.68 (0.27, 1.58), p=NS; [underlined: Meats DP] vs Vegetables DP (Ref): 0.63 (0.25, 1.48), p=NS; [underlined: Fruits, nuts, and Cantonese desserts DP] vs Vegetables DP (Ref): 0.42 (0.11, 1.21), p=NS; [underlined: Rich DP]: 1.84 (0.67, 4.11), p=NS; [underlined: Milk-S DP]: 1.76 (0.87, 3.27), p=NS; [underlined: Fruits DP]: 0.67 (0.22, 1.59), p=NS; [underlined: Meats-S DP]: 1.16 (0.52, 2.29), p=NS; [underlined: Prudent DP]: 0.72 (0.39, 1.27), p=NS | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, Pre-Pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: Folic acid supplementation; Previous PTB; Funding: National Natural Science Foundation of China; Guangzhou Science Technology and Innovation Commission; Guangdong Provincial Department of Science and Technology; Summary: When compared to alignment with the Vegetables DP, alignment with the Milk DP was associated with an increased risk of overall PTB, SPTB, and late PTB, but was not associated with risk of IPTB or early/moderate PTB.; When compared to alignment with the Vegetables DP, alignment with the Cereals, eggs, and Cantonese soups DP and the Fruits, nuts, and Cantonese desserts DP were associated with an increased risk of late PTB. They were not associated with risk of any other PTB outcomes.; When compared to alignment with the Vegetables DP, alignment with the Varied DP and the Meats DP was not associated with any PTB outcomes.; Greater alignment with the Rich DP was associated with a reduced risk of SPTB, but no other PTB outcomes.; Greater alignment with the Milk-S DP was associated with an increased risk of SPTB, but no other PTB outcomes.; Alignment with the Fruits DP, the Meats-S DP, the Moderate DP, and the Prudent DP was not associated with any PTB outcome.
Maldonado, 2022^17^; PCS, United States, MADRES; Analytic N=465; - Age (y): SRC Q1: 30.3±0.58, SRC Q4: 27.7±0.52, p=0.001; - Race/Ethnicity (%):; ○ Non-Hispanic and nonLatina: SRC Q1: 17.1, SRC Q4: 30.2, p=0.018; ○ US-born Hispanic/Latina: SRC Q1: 27.4, SRC Q4: 44.0, p=0.008; ○ Foreign-born Hispanic/Latina: SRC Q1: 55.6, SRC Q4: 25.9, p<0.001; - Socioeconomic position:; ○ Education (%); <HS: SRC Q1: 37.6, SRC Q4: 24.1, p=0.025; HS diploma or equivalent: SRC Q1: 35.0, SRC Q4: 44.0; >HS: SRC Q1: 34.2, SRC Q4: 20.7; ○ Total household income; <$15k: SRC Q1: 22.2, SRC Q4: 16.4; $15k-29k: SRC Q1: 23.1, SRC Q4: 25.0; >$30k: SRC Q1: 18.0, SRC Q4: 31.0, p=0.019; - Pre-pregnancy BMI: SRC Q1: 29.9 ± 0.67, SRC Q4: 27.6 ± 0.53, p=0.008; - Current DM (%):; ○ No DM: SRC Q1: 79.5, SRC Q4: 89.7, p=0.030; ○ GDM: SRC Q1: 8.6, SRC Q4: 8.6; ○ Preexisting DM: SRC Q1: 12.0, SRC Q4: 1.7, p=0.002; - Smoking (%): During pregnancy: 1.7% | SRC; VOF (quartiles of alignment; per 1 SD); 24 HR at: TM3; DP Description:; [underlined: Solid fat, refined grain, and cheese (SRC)]; - Higher intake of milk, cheese, fruit juices, tomatoes, other vegetables, white potatoes, legumes, seafood, refined grains, meat, processed meats, poultry, eggs, soy protein, nuts and seeds, oils, solid fats, added sugar.; - Lower intake of yogurt, citrus, melons, berries, other fruits, dark green vegetables, other red and orange vegetables, other starchy vegetables, whole grains.; [underlined: Vegetables, oils, and fruit (VOF)]; - Higher intake of milk, yogurt, cheese, citrus, melons, berries, other fruits, fruit juices, dark green vegetables, tomatoes, other red and orange vegetables, other vegetables, white potatoes, other starchy vegetables, legumes, seafood, whole grains, meat, processed meats, poultry, eggs, soy protein, nuts and seeds, oils, added sugar.; - Lower intake of refined grains, solid fats.; Outcomes:; PTB <37 GW | PTB; Multivariable logistic regression; OR (95% CI); [underlined: SRC]; Q2 vs Q1 (Ref): 0.93 (0.33, 2.63); Q3 vs Q1 (Ref): 0.73 (0.24, 2.23); Q4 vs Q1 (Ref): 0.82 (0.21, 3.15); p trend: 0.253; per 1 SD: 1.06 (0.57, 1.96), p=1.00; [underlined: VOF]; Q2 vs Q1 (Ref): 0.57 (0.22, 1.43); Q3 vs Q1 (Ref): 0.53 (0.21, 1.34); Q4 vs Q1 (Ref): 0.31 (0.10, 0.95); p trend: 0.049; per 1 SD: 0.61 (0.40, 0.93), p=0.031; Sensitivity analyses tested additional inclusion of child sex or PA and household income in the models which did not materially change results. | Key confounders accounted for:; Parity, Smoking, Age, Socioeconomic position, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: mean total energy intake; Funding: NIEHS; NIMHHD; EPA; Life Course Approach to Developmental Repercussions of Environmental Agents on Metabolic and Respiratory Health; NIH Office of the Director; Summary: Greater alignment with the SRC DP was not associated with risk of PTB.; Greater alignment with the VOF DP was associated with lower risk of PTB.
Martin, 2015^18^; PCS, United States, PIN; Analytic N=3,143; - Age (y, %): <25: 33.6%; 25-29: 28.1%; 30-34: 25.9%; ≥35: 12.4%; - Race/Ethnicity (%): 71.8% Non-black; 28.2% Black; - Socioeconomic position:; ○ Education (%): <HS: 12.4; HS: 22.7; >HS: 64.9; ○ FPL (%): <185%: 41.2; 185-350%: 20.2; >350%: 38.6; - Pre-pregnancy BMI: (%) <18.5: 4.8; 18.5-24.9: 54.3; 25.0-29.9: 19.3; ≥30: 21.5; - Smoking (%): Nonsmoker: 80.7; Smoker: 19.3 | Factor 1, Factor 2, Factor 3, Factor 4 (quartiles of alignment); FFQ at: 26-29 GW; DP Description:; [underlined: Factor 1]; Higher intake of fruits, tomatoes, broccoli, spinach, carrots, green salads, sweet potatoes, low-fat milk, yogurt, high-fiber and highly fortified cereals, nonfried chicken and fish, and wheat bread; [underlined: Factor 2]; Higher intake of beans, corn, French fries, hamburgers or cheeseburgers, white potatoes, fried chicken, spaghetti dishes, cheese dishes such as macaroni and cheese, cornbread or hushpuppies, processed meats, biscuits, and ice cream; [underlined: Factor 3]; Higher intake of collard greens, coleslaw or cabbage, red meats, fried chicken and fish, processed meats, cornbread or hushpuppies, eggs or egg biscuits, gravy, whole milk, and vitamin C–rich drinks such as Kool-Aid and Hi-C; [underlined: Factor 4]; Higher intake of shellfish, pizza, salty snacks, candies, pancakes, tacos or burritos, and cakes and cookies; Outcomes:; PTB: <37 GW; Spontaneous PTB: preceded by either preterm labor or premature rupture of the membranes resulting in delivery; Medically indicated PTB, defined as induction of labor or cesarean delivery without labor | PTB; Logistic Regression; OR (95% CI); [underlined: Factor 1]; Q4 vs Q1 (Ref): 0.87 (0.60, 1.27); Q3 vs Q1 (Ref): 1.07 (0.77, 1.49); Q2 vs Q1 (Ref): 1.20 (0.88, 1.64); [underlined: Factor 2]; Q4 vs Q1 (Ref): 1.53 (1.02, 2.30); Q3 vs Q1 (Ref): 1.37 (0.96, 1.96); Q2 vs Q1 (Ref): 1.01 (0.72, 1.42); [underlined: Factor 3]; Q4 vs Q1 (Ref): 1.55 (1.07, 2.24); Q3 vs Q1 (Ref): 1.32 (0.94, 1.86); Q2 vs Q1 (Ref): 1.25 (0.89, 1.74); [underlined: Factor 4]; Q4 vs Q1 (Ref): 1.13 (0.79, 1.63); Q3 vs Q1 (Ref): 1.18 (0.85, 1.64); Q2 vs Q1 (Ref): 0.94 (0.68, 1.31); Spontaneous PTB; Logistic Regression; OR (95% CI); [underlined: Factor 1]; All comparisons: NS; [underlined: Factor 2]; Q4 vs Q1 (Ref): 1.92 (1.08, 3.41); [underlined: Factor 3]; Q4 vs Q1 (Ref): 1.78 (1.07, 2.96); [underlined: Factor 4]; All comparisons: NS; Medically indicated PTB; All comparisons for all DP: NS | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, HH income in model, Pre-pregnancy BMI; Other covariates: Energy intake, marital status; Funding: NIH; Summary: Higher alignment with the Factor 2 DP and Factor 3 DP was associated with increased risk of PTB and with spontaneous PTB. Alignment with the Factor 1 or Factor 4 DP was not associated with PTB or spontaneous PTB. None of the DP were associated with Medically indicated PTB.
Miele, 2021^19^; PCS, Brazil, Preterm SAMBA; Analytic N=1,165; - Age (%): ≤19: 25.0; >35: 6.7; - Race/Ethnicity (%): Non-White: 60.3; White: 39.7; - Socioeconomic position:; ○ Education (%): <12y: 67.9; ○ Yearly income (%): ≤$12k: 73.9; ○ Employed (%): 50.2; - BMI at first visit (%): Overweight: 25.7; Obesity: 17.1; - Current HDP (%): PE: 7.5; - Current DM (%): GDM: 14.1 | Obesogenic DP, Intermediate DP, Vegetarian DP, & Protein DP vs Traditional DP; 24 HR at: 19-21 GW; DP Descriptions:; [underlined: Obesogenic DP]; Higher in ultra-processed and processed foods using NOVA classification (refined carbohydrate; fats; sweets); [underlined: Intermediate DP]; Lower consumption of same food groups as “Obesogenic DP”; [underlined: Vegetarian DP]; Higher in dairy; fruits; vegetables; [underlined: Protein DP]; Higher in fatty meats; eggs; beans; very low quantity of natural foods (using NOVA classification); [underlined: Traditional DP]; Higher in beans; meats; eggs; natural or minimally processed foods (using NOVA classification); Outcomes:; PTB <37 GW | PTB; Multiple logistic regression; OR; [underlined: Obesogenic DP] vs Traditional DP (Ref): 1.77, p≥0.05; [underlined: Intermediate DP] vs Traditional DP (Ref): 1.17, p≥0.05; [underlined: Vegetarian DP] vs Traditional DP (Ref): 1.35, p≥0.05; [underlined: Protein DP] vs Traditional DP (Ref): 2.11, p<0.05 | Key confounders accounted for:; Parity, Race and/or ethnicity, Age, Socioeconomic position, occupation, education not associated with outcome, Pre-pregnancy BMI; Other covariates: Region; Funding: Brazilian National Research Council; Bill and Melinda Gates Foundation; Summary: Alignment with the Protein DP was associated with higher risk of PTB when compared to the Traditional DP. Alignment with the Obesogenic DP, Intermediate DP, and Vegetarian DP was not associated with risk of PTB when compared to the Traditional DP.
Mitku, 2020^21^; PCS, South Africa, Mother and Child in the Environment Cohort; Analytic N=687; - Age (y): 20-29: 60.4%; - Socioeconomic position:; ○ HS graduate: 79.4%; ○ Unemployed: 81.5%; ○ No personal income: 45.3% | Energy foods and snacks DP, Spreads and fast foods DP, Butter, junk foods, and juices DP, Protein-rich foods, Starch foods DP, Nuts and rice foods DP, Vegetable-rich foods DP (continuous alignment, per unit increase); FFQ at: TM3; DP Description:; [underlined: Energy foods and snacks DP]; - Higher intakes of energy bars, energy drinks, ice cream, chocolate, drinking yogurt, milk drinks, milkshake, fruit salad, cheese sauce, cheese, chicken with skin, chips, cold meat, red meat, flamegrilled fast-food chicken, hot dogs, sausages, fizzy soft drinks, fruit juice, hamburgers, pizza, rusks.; - Lower intake of cooking oil.; [underlined: Spreads and fast foods DP]; - Higher intakes of dripping, salad dressing low fat, fat holsum, schnitzels, skimmed, chocolate spread, bunny chow, venison, fizzy diet soft drinks, fish steamed, whole wheat, dried fruit, red meat fat removed, cookies, fried fast food chicken, pasta, organ meat, nuts and peanuts, pizza, pies and sausage rolls, vetkoek, rusks, hot dogs, butter.; - Lower intake of fizzy soft drinks.; [underlined: Butter, junk foods, and juices DP]; - Higher intakes of butter, sweets, muffins, chips, mixed salad, fruit juice, fresh fruit, fizzy soft drinks, vetkoek, coffee creamer, cooking oil, hamburgers, cooked vegetables, cereals rice crispies.; - Lower intake of soft margarine.; [underlined: Protein-rich foods DP]; - Higher intakes of fried fish, fish tinned, fried fish in fat, eggs cooked or poached, white brown bread, potato chips, chicken with skin.; - Lower intakes of chicken without skin, red meat fat removed.; [underlined: Starch foods DP]; - Higher intakes of potato, breakfast cereals, potato with fat, legumes, full cream, cooked vegetables, cheese sauce, pasta, jam; [underlined: Nuts and rice foods DP]; - Higher intakes of peanut butter, nuts and peanuts, rice mealie rice; [underlined: Vegetable-rich foods DP]; - Higher intakes of vegetables, organ meat. Lower intakes of butter.; Outcomes:; Late PTB: 34-37 GW; Very or moderately PTB: <32 GW and 32-33 | Late PTB; Partial proportional odds model for severity levels of PTB; OR (95% CI); [underlined: Energy foods and snacks:] 0.797 (0.579, 1.097); [underlined: Spreads and fast foods:] 1.190 (0.889, 1.592); [underlined: Butter, junk foods and juice:] 0.988 (0.723, 1.350); [underlined: Protein-rich foods:] 0.970 (0.729, 1.291); [underlined: Starch foods:] 0.851 (0.666, 1.088); [underlined: Nuts and rice foods:] 0.979 (0.751, 1.276); [underlined: Vegetable rich foods:] 0.730 (0.531, 0.981), p<0.05; Very or moderately PTB; Partial proportional odds model for severity levels of PTB; OR (95% CI); [underlined: Energy foods and snacks:] 0.797 (0.579, 1.097); [underlined: Spreads and fast foods:] 1.190 (0.889, 1.592); [underlined: Butter, junk foods and juice:] 0.988 (0.723, 1.350); [underlined: Protein-rich foods:] 0.970 (0.729, 1.291); [underlined: Starch foods:] 2.090 (1.158, 3.769), p<0.05; [underlined: Nuts and rice foods:] 0.248 (0.099, 0.621), p<0.05; [underlined: Vegetable rich foods:] 0.730 (0.531, 0.981), p<0.05 | Key confounders accounted for:; Parity, Age, Socioeconomic position: maternal education, employment, maternal annual income; Other covariates: infant sex; Funding: National Research Foundation; Medical Research Council South Africa; AstraZeneca South Africa; University of KwaZulu-Natal; DAAD (German Academic Exchange Program); Summary: Higher alignment with the vegetable rich foods DP was associated with lower risk of PTB.; The starch foods DP and nuts and rice foods DP were not associated with PTB.; Higher alignment with the nuts and rice foods DP and the vegetable rich foods DP was associated with lower risk of very and moderately PTB. Higher alignment with the starch foods DP was associated with higher risk of very and moderately PTB.; The energy foods and snacks DP, spreads and fast foods DP, butter, and junk foods and juice DP were not associated with either PTB or very or moderately PTB.
Paknahad, 2019^23^; PCS, Iran (Islamic Rep. of), Selseleh County Health Centers; Exposure N=HCLF: 34, HCHF: 55, Comparator N=61; - Age (y): HCLF: 27.67±6.1; HCHF: 27.70±4.1; High fiber: 29.27±5.8; - Socioeconomic position: Job (%): Homemaker: HCLF: 97.1; HCHF: 96.4; High fiber: 96.7; Employed: HCLF: 2.9; HCHF: 3.6; High fiber: 3.3; - Pre-pregnancy BMI: Baseline BMI: HCLF: 26.2; HCHF: 26.8; High fiber: 25.8; - Current DM (%):; ○ T1 or T2 DM: 0.0; ○ GDM: HCLF: 4.0; HCHF: 2.0; High fiber: 0.7 | HCLF DP & HCHF DP vs High fiber DP; FFQ at: TM1; DP Description:; [underlined: High Carbohydrate-Lower Fat (HCLF) DP]:; High intake of potato; fried potato; flour; egg; cooked carrots; pickles; noodle soup; beans; pomegranate; corn and maize; lentils; low-fat milk; lettuce; and raw carrot; [underlined: High Carbohydrate-Higher Fat (HCHF) DP]:; High intake of pea; soybean; fish; cabbage; cooked spinach; vegetable; high-fat milk; butter; tomato; cucumber; soup; cooked beans; and diluted yogurt; [underlined: High fiber DP]:; High intake of cantaloupe; melon; peach; nectarine; green tomatoes; plums; watermelons; pears; apricots; Outcomes:; PTB <37 GW | PTB; Linear regression; OR (95% CI); [underlined: HCLF] vs High fiber (Ref): 2.33 (0.89, 6.11), p=0.08; [underlined: HCHF] vs High fiber (Ref): 0.78 (0.31, 1.93), p=0.59 | Key confounders accounted for:; Age, Socioeconomic position, Pre-Pregnancy BMI, DM in current pregnancy; Other covariates: disease history, catching diseases, energy intake; Funding: NR; Summary: Alignment with the HCLF DP or the HCHF DP, compared to alignment with the High fiber DP, was not associated with risk of PTB.
Rasmussen, 2014^25^; PCS, Denmark, DNBC; Analytic N=59,918; - Age (y): 21-39: 98%; - Socioeconomic position:; ○ Of medium level of proficiency or unskilled: 51%; ○ Lived in settlements of >10k inhabitants: 60%; - Current HDP: PE: n=1,666; - Current DM: GDM: n=1,002; - Smoking (%): Occasional or daily: 25% | Alcohol DP, Vegetable/Prudent DP, Western DP, Seafood DP, Nordic DP, Sweets DP, Rice/Pasta/Poultry DP (quintiles of alignment); FFQ at: 25 GW; DP Description:; [underlined: Alcohol pattern]; Higher intake of soya, root, berries, wine, liquor, and beer; [underlined: Vegetable/Prudent pattern]; Higher intake of cabbage, onion, mushroom, corn, salad, tomato, root, other vegetables, legumes, other fruit; [underlined: Western pattern]; Higher intake of potatoes, French fries, bread white, pork, beef veal, meat mixed, cold meat, dressing sauce, butter, margarine; [underlined: Seafood pattern]; Higher intake of fish, beef/veal and lamb, oil, egg, fermented milk, yogurt, Asian vegetables, other vegetables, tomato, onion; [underlined: Nordic pattern]; Higher intake of dark bread, Nordic fruit, hard cheese, banana, dried fruit, sweet spread; [underlined: Sweets pattern]; Higher intake of white bread, margarine, snack, sugar cakes, sweet spread, candy, dairy dessert, and chocolate; [underlined: Rice/Pasta/Poultry pattern]; Higher intake of ice, pasta, and poultry; Outcomes:; PTB: <37 GW (Induced, Spontaneous); Early PTB: <32 GW; Late PTB: <38 GW; Very late PTB: <39 weeks | Induced PTB; Multivariate logistic regression; OR (95% CI); [underlined: Western DP]; Quintile 5 vs Quintile 1 (Ref): 1.70 (1.37, 2.11), p-trend <0.001; [underlined: Seafood DP]; Quintile 4 vs Quintile 1 (Ref): 0.62 (95% CI: 0.50, 0.79); Quintile 5 vs Quintile 1 (Ref): 0.90 (95% CI: 0.72, 1.11), p-trend=0.2; [underlined: Vegetable DP]; Quintile 5 vs Quintile 1 (Ref): >1, p-trend=0.03; [underlined: Alcohol DP]; Quintile 5 vs Quintile 1 (Ref): >1, p-trend=0.06; [underlined: Nordic DP]; Quintile 5 vs Quintile 1 (Ref): <1, p-trend=0.8; [underlined: Sweets DP]; Quintile 5 vs Quintile 1 (Ref): >1, p-trend=0.7; [underlined: Rice/Pasta/Poultry DP:]; Quintile 5 vs Quintile 1 (Ref): <1, p-trend=0.8; Spontaneous PTB; Multivariate logistic regression; OR (95% CI); [underlined: Western DP]; Quintile 5 vs Quintile 1 (Ref): 1.18 (0.99, 1.39), p=0.02; [underlined: Seafood DP]; Quintile 5 vs Quintile 1 (Ref): <1, p-trend=0.045; [underlined: Alcohol DP]; Quintile 5 vs Quintile 1 (Ref): >1, p-trend=0.9; [underlined: Nordic DP]; Quintile 5 vs Quintile 1 (Ref): <1, p-trend=0.5; [underlined: Sweets DP]; Quintile 5 vs Quintile 1 (Ref): <1, p-trend=0.08; [underlined: Rice/Pasta/Poultry DP]; Quintile 5 vs Quintile 1 (Ref): <1, p-trend=0.2; Early, Late, and Very late PTB results; NR | Key confounders accounted for:; Parity, Smoking, Age, Socioeconomic position, Pre-pregnancy BMI, Current HDP, DM in current pregnancy; Other covariates: maternal height, civil status**Authors provided unadjusted results, only (presented above), noting, “This association was relatively unaffected when adjusting for confounders.”; Funding: Danish Council for Strategic Research; the Danish Council for Independent Research; the Lundbeck foundation; and the European Union (EU) Integrated Research Project EARNEST; The DNBC has been financed by the March of Dimes Birth Defects Foundation, the Danish Heart Association, the Danish Medical Research Council, and the Sygekassernes Helsefond, Danish National Research Foundation, Danish Pharmaceutical Association, Ministry of Health, National Board of Health, Statens Serum Institut.; Summary: Higher alignment with the Western DP was associated with a greater risk of induced or spontaneous PTB. Higher alignment with the Seafood DP was associated with a lower risk of PTB. There was no association between the Alcohol DP, Vegetable DP, Sweets DP, or Rice/Pasta/Poultry DP and risk of PTB.
Wang, 2021^27^; PCS, China, ISPOHC; Analytic N=4,361; - Age (y): (%) <35: 86.5, ≥35: 13.5; - Socioeconomic position:; ○ Education level (y, %): ≤9 y: 15.4, ≥16 y: 11.6; ○ Family income (Yuan, %): <100k: 17.1, ≥200k: 41.7; - Pre-pregnancy BMI: (%) <18.5: 12.4, ≥24: 17.2 | AFP; Vegetarian pattern; Dairy and Egg pattern (tertiles of alignment); FFQ at: NR (participants evenly distributed across first, second, and third trimesters); DP Description:; [underlined: Animal Food Pattern (AFP)]; Higher intake of fish, poultry, livestock; [underlined: Vegetarian Pattern]; Higher intake of fruits, potatoes and their products, cereals and their products, vegetables, thallophytes, salted products, beans and their products, nuts.; [underlined: Dairy and Egg Pattern]; Higher intake of dairy products, eggs; Outcomes:; PTB | PTB; Logistic regression; OR (95% CI); [underlined: AFP]; T2 vs T1 (Ref): 1.470 (0.990, 2.183), p=0.056; T3 vs T1 (Ref): 1.899 (1.299, 2.776), p=0.001; [underlined: Vegetarian Pattern]; T2 vs T1 (Ref): Data NR, p=0.534; T3 vs T1 (Ref): Data NR, p=0.725; [underlined: Dairy and Egg Pattern]; T2 vs T1 (Ref): Data NR, p=0.611; T3 vs T1 (Ref): Data NR, p=0.216 | Key confounders accounted for:; Age, Socioeconomic position, annual family income, Pre-pregnancy BMI; Other covariates: other DPs, drinking during pregnancy, sex of baby; Funding: Three-year Plan of Shanghai Municipal Public Health System; Dietary Nutrition Research and Education Foundation of Danone Nutrition Center; Top Young Talents in Shanghai; Summary: Greater alignment with the AFP pattern was associated with higher risk of PTB. Alignment with the Vegetarian Pattern or the Dairy and Egg Pattern was not associated with risk of PTB.
Yisahak, 2021^29^; PCS, United States, NICHD; Fetal Growth Studies-Singletons Analytic N=1,948; PCA pattern 1:; - Age (y): Q1: 29.5±5.4, Q4: 25.4±5.4, p<0.001; - Race/Ethnicity (%): p<0.001; ○ NHW: Q1: 16, Q4: 13; ○ NHB: Q1: 19, Q4: 50; ○ Hispanic: Q1: 29, Q4: 29; ○ AAPI: Q1: 36, Q4: 8; - Socioeconomic position (%):; ○ Education <HS: Q1: 13, Q4: 15; HS or equivalent: Q1: 15, Q4: 29; Postgraduate: Q1: 19, Q4: 9, p<0.001; ○ Income ($) <30k: Q1: 28, Q4: 50; ≥100k: Q1: 24, Q4: 14, p<0.001; ○ Full-time school or work: Q1: 65, Q4: 68; ○ Insurance (private/managed care): Q1: 66, Q4: 43, p<0.001; - Pre-pregnancy BMI: Q1: 24.8±5.0, Q4: 25.5±5.1, p<0.001; - Smoking (%): Smoking with obesity: n=17; Smoking without obesity: 0.0 | PCA Patterns 1 and 2 (quartiles of alignment); FFQ at: 8-13 GW; DP Description:; [underlined: PCA pattern 1]; Higher intake of solid fat, nonwhole grains, white potatoes, meat (from beef, pork, veal, lamb, and game), cheese.; [underlined: PCA pattern 2]; Higher intake of other vegetables (not potatoes, starchy, orange, or dark-green vegetables), dark-green vegetables, orange vegetables, seafood high in omega-3 fatty acids, seafood low in omega-3 fatty acids.; Outcomes:; PTB <37 GW | PTB; Logistic regression; OR (95% CI); [underlined: PCA pattern 1]; Q2 vs Q1 (Ref): 1.31 (0.69, 2.51); Q3 vs Q1 (Ref): 1.57 (0.75, 3.27); Q4 vs Q1 (Ref): 1.60 (0.55, 4.65); p trend: 0.41; [underlined: PCA pattern 2]; Q2 vs Q1 (Ref): 0.95 (0.52, 1.74); Q3 vs Q1 (Ref): 0.87 (0.44, 1.72); Q4 vs Q1 (Ref): 0.76 (0.35, 1.61); p trend: 0.44 | Key confounders accounted for:; Parity, Smoking, Race and/or ethnicity, Age, Socioeconomic position, income, current job/student status, insurance coverage, Pre-pregnancy BMI; Other covariates: height, marital status, study site, infant sex, total weekly PA, total daily energy intake; Funding: NICHD; American Recovery and Reinvestment Act; Summary: Alignment with PCA pattern 1 and PCA pattern 2 were not associated with risk of PTB
Reduced Rank Regression
Alves-Santos, 2019^1^; PCS, Brazil, Rio de Janeiro Federal University; Analytic N=189; - Age (y): 26.7±5.5; - Socioeconomic position:; ○ Per capita family income (US dollars/mo): 524.4±370.0; ○ Education (y): 8.7±2.9; - Pre-pregnancy BMI: 25.13±4.5; ○ ≥25 (%): 42.0; - Current DM (%): Free from chronic disease: 100; - Smoking (%): 6.2 | Fast food and Candies DP; Vegetables and Dairy DP; Beans, Bread, and Fat DP (tertiles of alignment: High, Medium vs Low); FFQ at: TM1; DP Description:; Fast Food and Candies DP: High intakes of fast food and snacks; cakes, cookies, or crackers; and candies or desserts; low intakes of rice, beans, vegetables spices, and green vegetables or legumes; Vegetables and Dairy DP: High intakes of green vegetables or legumes, dairy products, fish, tea, fruits or fruit juices, and candies or desserts; low intakes of bread, sweetened and diet soda, and table sugar; Beans, Bread, and Fat DP: High intakes of beans; cakes, or cookies, or crackers; bread and fats used as spreads; low intakes of fish, fruit or fruit juices, and noodles, pasta, roots, or tubers; Outcomes:; PTB <37 GW | PTB; Multiple logistic regression; OR (95% CI); [underlined: Fast Food and Candies DP]; Medium vs Low (Ref): 3.01 (0.83, 10.88), p=0.091; High vs Low (Ref): 1.42 (0.35, 5.75), p=0.617; [underlined: Vegetables and Dairy DP]; Medium vs Low (Ref): 0.81 (0.25, 2.59), p=0.726; High vs Low (Ref): 0.24 (0.06, 0.97), p=0.046; [underlined: Beans, Bread, and Fat DP]; Medium vs Low (Ref): 0.69 (0.21, 2.19), p=0.536; High vs Low (Ref): 0.51 (0.14, 1.84), p=0.307 | Key confounders accounted for:; Smoking, Age, Socioeconomic position; Other covariates: Alcohol consumption; TM1 leisure physical activity; Funding: Carlos Chagas Filho Research Foundation from the State of Rio de Janeiro (FAPERJ); Summary: High alignment with the Vegetables and Dairy DP, but not medium alignment, was associated with a reduced risk of PTB when compared to low alignment. There was no association between alignment with the Fast Food and Candies DP or the Beans, Bread, and Fat DP and risk of PTB.
Lecorguillé, 2020^13^; PCS, France, EDEN Mother-Child Study; Analytic N=1,638; - Age (y): 29.7±4.9; - Socioeconomic position:; ○ Education (%): Lower secondary school: 25.9, Upper secondary school: 17.9, Post-secondary: 22.6, Tertiary: 33.6; ○ Employment status (%): Employed: 76.6, Student: 2.6, Staying at home: 20.7; ○ Monthly household income, Euros (%): <1,501: 15.1, 1,501-2,300: 28.4, 2,301-3k: 26.9, >3k: 29.6; - Pre-pregnancy BMI (%): Underweight: 8.3; Overweight: 18; Obesity: 7.6; - Current DM (%): Diabetes before pregnancy: 0.0; - Smoking (%): During pregnancy: No: 74.2, 1-9/d: 21.2, ≥10/d: 4.6 | Varied and balanced DP, Vegetarian tendency DP, Bread and starchy food DP (continuous, per 1 SD increase); FFQ at: <28 GW (~15 GW); DP Description:; [underlined: Varied and balanced DP]; - Higher intake of low-fat milk, other vegetables, fish, meat, chicory, leek, cabbage, eggs and egg dishes, cereals, broccoli, liver.; - Lower intake of snacks and confectionary, SSB.; [underlined: Vegetarian tendency DP]; - Higher intake of other vegetables, chicory, cereals, fruits, bread.; - Lower intake of meat, liver.; [underlined: Bread and starchy food DP]; - Higher intake of bread, rice, pasta, and others, sandwich.; - Lower intake of low-fat milk, fruits, fruit juice, SSB.; Outcomes:; PTB <37 GW | PTB; Logistic regression; OR (95% CI); [underlined: Varied and balanced]; 1.10 (0.92, 1.32); [underlined: Vegetarian tendency]; 0.79 (0.65, 0.98); [underlined: Bread and starchy food]; 1.02 (0.81, 1.28) | Key confounders accounted for:; Parity, Smoking, Age, Socioeconomic position, employment status, monthly household income, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: center, vitamin supplementation, infant sex; Funding: Foundation for Medical Research; National Agency for Research; National Institute for Research in Public Health; French Ministry of Health; French Ministry of Research; INSERM Bone and Joint Diseases National Research; Human Nutrition National Research Programs; Paris-Sud University; Nestle; Fench National Institute for Population Health Surveillance; French National Institute for Health Education; EU FP7 Programs; Diabetes National Research Program; French Agency for Environmental Health Safety; Mutuelle Generale de l’Education Nationale; French National Agency for Food Security; French-Speaking Association for the Study of Diabetes and Metabolism; Summary: Alignment with a vegetarian tendency DP was associated with lower risk of PTB. Alignment with a varied and balanced DP or a bread and starchy food DP was not associated with risk of PTB.

a #±# indicates mean ± standard deviation unless otherwise noted. Abbreviations: $#k: # thousands of dollars; 24 HR: 24 hour recall; AAPI: American Asian/Pacific Islander; aOR: adjusted odds ratio; AHEI: Alternate Healthy Eating Index; AHEI-P: Alternate Healthy Eating Index for Pregnancy; aMED: alternative Mediterranean diet; BIGCS: Born in Guangzhou Cohort Study; BMI: body mass index; CARRDIP: Cardiovascular Risk Reduction Diet in Pregnancy study; CI: confidence interval; CLIMB: Complex Lipids in Mothers and Babies cohort; d: day(s); DASH: Dietary Approaches to Stop Hypertension; DHA: docosahexaenoic acid; DM: diabetes mellitus; DNBC: Danish National Birth Cohort; DP: dietary pattern(s); EPA: eicosapentaenoic acid; ESTEEM: Effect of Simple Targeted Diet in Pregnant Women With Metabolic Risk Factors on Pregnancy Outcomes; EVOO: extra virgin olive oil; FFQ: food frequency questionnaire; FPL: Federal Poverty Level; g: gram(s); GDM: gestational diabetes mellitus; GUSTO: Growing Up in Singapore Towards healthy Outcomes; GW: gestational weeks; GWG: gestational weight gain; HDP: hypertensive disorders of pregnancy; HEI: Healthy Eating Index; HEI-SGP: Healthy Eating Index for pregnant women in Singapore; HTN: hypertension; HS: high school; IMPACT BCN: Improving Mothers for a Better Prenatal Care Trial Barcelona; IQR: interquartile range; ISPOHC: Iodine Status in Pregnancy and Offspring Health Cohort; ITT: intent-to-treat; kg: kilogram(s); L: liter; LIFT: Lifestyle Intervention For Two; MADRES: Maternal and Developmental Risks from Environmental and Social Stressors study; MEDAS: Mediterranean Diet Adherence Screener; MedDiet: Mediterranean diet; min: minute(s); mL: milliliter; mo: month; MoBa: Norwegian Mother and Child Cohort Study; MOMFIT: Maternal Offspring Metabolics Family Intervention Trial; MUFA: monounsaturated fatty acid; N: sample size; NFFD: Norwegian Fit for Delivery; NHB: Non-Hispanic Black; NHW: Non-Hispanic White; NIH: National Institutes of Health; NICHD: National Institute of Child Health and Development; NOK: Norwegian Krone; NR: not reported; NS: nonsignificant; nuMoM2b: Nulliparous Pregnancy Outcomes Study: Monitoring Mothers-to-Be; OMNI: Optimal Macronutrient Intake; OR: odds ratio; PA: physical activity; PCA: principal component analysis; PCS: prospective cohort study; PE: preeclampsia; PETALS: Pregnancy Environmental and Lifestyle Study; PIN: Pregnancy, Infection, and Nutrition Study; PP: per-protocol; pt: point; PTB: preterm birth; PUFA: polyunsaturated fatty acid; Q#: quartile; RCT: randomized controlled trial; Ref: reference; RR: relative risk; SD: standard deviation; SEIFA IRSD: Socio-economic Index for Areas— Index of Relative Socio-economic Disadvantage; SES: socioeconomic status; SFA: saturated fatty acid; SGA: small for gestational age; SSB: sugar-sweetened beverage(s); svg: serving; T#: tertile; T1 or T2 DM: Type 1 or Type 2 DM; TEI: total energy intake; TM#: trimester; U.K.: United Kingdom; vs: versus; wk: week(s); y: year(s)

Table 8 Risk of bias for randomized controlled trials examining dietary patterns consumed during pregnancy and preterm birth^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Al Wattar, 2019^31^ | LOW | LOW | LOW | LOW | LOW | LOW
Assaf-Balut, 2017^32^ | LOW | HIGH | LOW | LOW | LOW | HIGH
Assaf-Balut, 2019^33^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | HIGH
Crovetto, 2021^34^ | LOW | HIGH | LOW | LOW | SOME CONCERNS | HIGH
Dodd, 2019^35^ | LOW | LOW | LOW | LOW | LOW | LOW
Gallagher, 2018^36^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Khoury, 2005^37^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Melero, 2020^38^ | LOW | HIGH | LOW | LOW | LOW | HIGH
Van Horn, 2018^39^ | LOW | LOW | LOW | LOW | LOW | LOW
Zhao, 2022^40^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 9 Risk of bias for non-randomized controlled trials examining dietary patterns consumed during pregnancy and preterm birth^a^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Al Wattar, 2019^31^ | SERIOUS | LOW | SERIOUS | SERIOUS | LOW | LOW | SERIOUS | SERIOUS

a Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool (https://www.riskofbias.info/welcome/home/current-version-of-robins-i)” ( Sterne JAC, Hernán MA, Reeves BC, ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 10 Risk of bias for observational studies examining dietary patterns consumed during pregnancy and preterm birth^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Alves-Santos, 2019^1^ | HIGH | LOW | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Bodnar, 2024^2^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Chia, 2016^3^ | HIGH | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Chia, 2018^4^ | HIGH | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
de Seymour, 2022^5^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Englund-Ögge, 2014^6^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Fulay, 2018^7^ | LOW | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Grieger, 2014^8^ | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Haugen, 2008^9^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Hillesund, 2014^11^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Hillesund, 2018^10^ | LOW | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Hu, 2023^12^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Lecorguillé, 2020^13^ | SOME CONCERNS | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Li, 2021^14^ | HIGH | SOME CONCERNS | LOW | HIGH | HIGH | LOW | SOME CONCERNS | HIGH
Lu, 2018^15^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Makarem, 2022^16^ | SOME CONCERNS | LOW | LOW | HIGH | HIGH | LOW | HIGH | HIGH
Maldonado, 2022^17^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Martin, 2015^18^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Miele, 2021^19^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Mikkelsen, 2008^20^ | HIGH | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Mitku, 2020^21^ | HIGH | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Navarro, 2019^22^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Parisi, 2020^24^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | HIGH | HIGH
Paknahad, 2019^23^ | HIGH | SOME CONCERNS | LOW | HIGH | HIGH | LOW | SOME CONCERNS | HIGH
Rasmussen, 2014^25^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Robinson, 2021^26^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Wang, 2021^27^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Yee, 2020^28^ | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Yisahak, 2021^29^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Zhu, 2021^30^ | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.