# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for 2 systematic reviews assessing the relationship between dietary patterns consumed during pregnancy and birth weight and gestational age.^†^ The literature search (Appendix 4) yielded 1,594 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 1,075 titles, 198 abstracts, and 265 full-texts articles. Reasons for full-text exclusion are in Appendix 5. Nine additional articles were included from the existing systematic review^‡^ and 1 additional article was identified from the manual search. The body of evidence included 40 articles.

† Fisher JO, Abrams SA, Andres A, Dietary Patterns Consumed During Pregnancy and Birth Weight: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR27

‡ Raghavan R, Dreibelbis C, Kingshipp BJ, Dietary Patterns before and during Pregnancy and Gestational Age- and Sex-Specific Birth Weight: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0104.

Figure 2 Literature search and screening flowchart

Literature search and screen flowchart The literature searches in PubMed, Embase, Cochrane, CINAHL, and Scopus retrieved 2,918 records after removing duplicates. 1 additional article was found with manual search methods. 9 were included from an existing review. 1,075 titles, 198 abstracts, and 265 full-texts were excluded. 40 articles were included in the systematic review. (Grouped Object)

## Description of the evidence

This systematic review included 40 articles from 30 studies: 30 articles from 22 prospective cohort studies (PCS),^1–30^ 10 articles from 8 randomized controlled trials (RCT),^31–40^ and one article from one non-randomized controlled trial (NRCT),^38^ that address the relationship between dietary patterns during pregnancy and preterm birth. Articles were from countries classified as high or very high on the HDI,^*^ published between January 1980 and January 2024, and enrolled participants during pregnancy who were generally healthy, including those with overweight and obesity.

* The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead ( The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-andlending-groups ).

The analytic sample size for RCT and NRCT ranged from 196^36^ to 1,137,^31^ although most had more than 600 participants.^31–35^ For cohort studies, the analytic sample size ranged from 94^24^ to 66,000,^6^ and most had more than 1,000 participants.^2,4,6,7,9,11–16,18,20,25–29^

Twelve articles from 8 studies were conducted in the U.S.^2,7,14,16–18,26,28–30,36,39^; 5 articles from 5 studies were conducted in China^5,12,15,27,40^; 5 articles from 3 studies in Norway^6,9–11,37^; 4 articles from 2 studies in Spain^32–34,38^; 2 articles from 2 studies each in Brazil^1,19^ and Australia^8,35^; 2 articles from 1 study each in Singapore^3,4^ and Denmark^20,25^; and 1 study each from France,^13^ Italy,^24^ Iran,^23^ Ireland,^22^ South Africa,^21^ and the U.K.^31^

### Participant characteristics

#### Age

The mean or median age of participants ranged from approximately 27 to 34 years.^1–11,13–18,20,22–25,30–33,35–40^ Three studies reported that approximately 7%,^19^ 14%,^27^ and 25%^12^ of participants were older than 35 years and one study reported a median age of 37 years.^34^ Another study reported 60% of participants were between age 20 and 29 years.^21^ Four studies excluded participants younger than 21 years^20,37^ or 18 years.^24,30^ Another study conducted in Brazil reported 25% of participants were 19 years or younger.^19^

#### Health status

##### Pre-pregnancy BMI

Most articles enrolled participants predominantly without overweight or obesity.^1–7,9–15,18–20,22,24,26,27,32–35,37,38,40^

One-quarter of the articles enrolled participants exclusively^36^ or predominantly with pre-pregnancy or early pregnancy BMI ≥25 kg/m^2^ ^8,16,17,23,28–30,36^ or ≥30 kg/m^2^. ^31,39^

##### Diabetes mellitus in the current pregnancy

Seven articles included approximately 1-7% participants with pre-existing diabetes mellitus^2,11,16,17,26,28,34^ and another 15 articles excluded participants with pre-existing diabetes mellitus.^1,3,4,6,7,10,13–15,23,30,35–37,39^ One additional article excluded participants with gestational diabetes mellitus (GDM).^33^ Nineteen articles^3,5,7,10,11,14,17,19,23–25,28,31,32,34–36,38,40^ reported a prevalence of GDM (approximately 1-28%). Of those, 8 had a prevalence greater than 12%.^3,5,19,31,32,35,38,40^ Nine articles did not report on diabetes mellitus during pregnancy.^8,9,12,18,20–22,27,29^

##### Current hypertensive disorders of pregnancy

Four articles excluded participants with chronic or pre-pregnancy hypertension^15,16,20,37^ and another 4 articles reported approximately 1-4% prevalence of chronic or pre-pregnancy hypertension.^11,26,28,30^ Seventeen articles reported any hypertensive disorders of pregnancy (HDP). Of these, 5 reported 0-23% of participants had HDP (unspecified).^3,7,24,28,38^ Approximately one-third^14,16,32–35^ of articles reported 1.5-3.7% of participants had gestational hypertension and nearly two-thirds^2,5,10,14,19,25,31–35^ reported 1.7-10.8% of participants had preeclampsia or eclampsia. One additional article reported 26.5% of participants had chronic hypertension, gestational hypertension, pre-eclampsia, or GDM.^4^ Twenty-two articles did not report on HDP.^1,6,8,9,12,13,17,18,21–23,27,29,36,39,40^

##### Smoking

Six articles did not describe participant smoking status.^5,19,21,23,27,31^ Twenty-seven articles reported that 0-25% of participants smoked during pregnancy.^1,3,4,6,7,9–13,17,18,20,22,24–26,30,32–40^ Of those, nearly one-fifth included no smokers,^9,20,36,37,39^ one-quarter reported ≤3% of participants currently smoked,^3,4,12,17,30,38,40^ two-fifths included 4-12% current smokers,^1,6,7,10,11,24,26,32–35^ and the rest reported 19-25% of participants currently smoked.^13,18,22,25^

One additional U.S.-based study^14,29^ excluded participants with BMI <30 kg/m^2^ who smoked but did not report smoking status among participants with BMI ≥30 kg/m^2^. Three articles stated 32-42% of participants had ever smoked or smoked before pregnancy^8,16,28^ and an additional article reported approximately 15% of participants had ever smoked or smoked before pregnancy.^2^ Another article reported approximately 30% of participants were exposed to passive smoking.^15^

#### Race and/or ethnicity

About one-third of articles did not report race and/or ethnicity.^1,6,9,11,13,20–25,27,40^

White: Of the articles that did report race and/or ethnicity, nearly one-half of articles reported participants were predominantly (64-84%)^2,7,8,10,16,26,28,32–35,39^ or exclusively^37,38^ White.

Asian: Nine articles reported 2-44% of participants were Asian,^7,14,16,28–31,34,35^ with 3 articles specifying that Pacific Islanders were included.^14,29,30^ Five additional articles reported 90-100% of participants were Asian.^3–5,12,15^

Hispanic: Ten articles reported 11-44% Hispanic ethnicity participants.^2,14,16,28–30,32,33,36,39^ Two additional studies included 77%^17^ or 100%^38^ Hispanic participants.

Black: Thirteen articles reported 2-34% of participants were Black.^2,7,14,16,18,26,28–31,34,36,39^

Other: One article from Brazil reported that the majority of participants were not White,^19^ but provided no additional information about participant race and/or ethnicity. No articles reported American Indian or Alaska Native participants.

#### Socioeconomic position

##### Education

Most articles reported that the majority of participants had at least some higher education or were described as “well educated”.^2–6,10–16,18,26–30,32,33,36,37^ Seven articles reported that most participants had a high school education or less.^1,7,17,19,21,22,38^ One-quarter of articles did not report education level of participants.^8,9,20,23,25,31,34,35,39,40^

##### Income, Occupation, or Other

One-fifth of the articles did not report on income, occupation, or another measure of socioeconomic position.^3,9,11,14,16,20,31,37^

Of the 13 articles that reported occupation, the majority of participants were employed in 10 articles^2,10,13,19,24,29,30,32,33,40^ and 3 articles noted that participants were mostly unemployed.^21,23,38^

Twenty articles reported income. Eleven stated that the majority of participants had at least a “middle” income according to income level cutoffs specific to each country.^5–7,10,12,13,26,27,30,36,39^ Seven articles stated that a majority of participants had below a “middle” income.^1,4,15,17,19,22,29^ One article from the nuMOM2b study^28^ reported that 12-56% of participants across exposure levels had incomes <200% of the Federal poverty level (FPL) and a second study reported that most participants had ≥185% the FPL.^18^

Seven articles reported a socioeconomic position measure other than education, income, or occupation. One Australian trial noted that approximately 17% of the participants were classified as most disadvantaged based on the Socio-economic Index for Areas—Index of Relative Socio-economic Disadvantage,^35^ while in 2 other articles the majority scored “high”^34^ or “lowest”^8^ on a socioeconomic status index. In a U.S. study, most participants had private insurance,^2,26^ while another study reported that approximately 26% of participants had public insurance.^28^ Finally, the majority of participants in a Danish study^25^ reported a “medium level of proficiency” or “unskilled” socioeconomic status.

### Intervention/exposures and comparators

A dietary pattern was defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they were habitually consumed.

Dietary patterns were assessed using experimental diets in 10 RCT and one NRCT^31–40^, index/score analysis in 15 articles,^4,7,9–11,14,16,18,20,22,24,26,28–30^ factor/cluster analysis in 15 articles,^2,3,5,6,8,12,15,17–19,21,23,25,27,29^ and reduced regression in 2 articles.^1,13^ The dietary pattern components are detailed in Table 5 and visualized in Appendix 6.

Table 5 Dietary Pattern Components^*^ * Abbreviations: d: day; DASH: Dietary Approaches to Stop Hypertension; DHA: docosahexaenoic acid; DP: dietary pattern(s); EPA: eicosapentaenoic acid; EVOO: extra virgin olive oil; MUFA: monounsaturated fatty acids; OMNI: Optimal Macronutrient Intake; PCA: principal component analysis; PUFA: polyunsaturated fatty acids; SFA: saturated fatty acids; SSB: sugar-sweetened beverages; svg: serving; T#: Trimester; wk: week

Reference | Dietary pattern | Dietary pattern components
Experimental Diet
Al Wattar, 2019^31^ | Mediterranean-style supplemented w/ mixed nuts and EVOO | Positive: Olive oil (as main fat and svg/d); Nuts (including peanuts) Vegetables; Fruit (including juice); Pulses; Fish or shellfish; White meat over red meat; Negative: Red or processed meat; Butter, margarine, or cream; SSB; Commercial sweets or pastries
Assaf-Balut, 2017^32^; Assaf-Balut, 2019^33^ | Mediterranean-style supplemented w/ pistachios and EVOO | Positive: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; Negative: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries
Crovetto, 2021^34^ | Mediterranean-style | Positive: EVOO; walnuts; vegetables; fresh fruit; dairy products; whole grains; sofrito; legumes; fish; fatty fish; white meat; Negative: Refined grains; red meat; processed meat; soda drinks; commercial bakery foods, sweets, and pastries; butter, margarine, or cream
Dodd, 2019^35^ | Healthy Eating Index | Positive: Vegetables; fruit; dairy
Gallagher, 2018^36^ | Healthy Eating Index-2010 | Positive: Vegetables; fruits; whole grains; total protein foods; plant proteins; seafood; dairy; fatty acids; Negative: Refined grains; energy from added sugars, solid fats, alcohol; sodium
Khoury, 2005^37^ | Intervention diet | Positive: Fish and fish products; fatty fish and fish products; rapeseed-based margarine; oils; olive oil; rapeseed oil; nuts, olives, and seeds; vegetables; fruits; Negative: Fatty milk; meat and meat products; fatty minced meat; butter; hard margarines
Melero, 2020^38^ | Mediterranean-style supplemented w/ pistachios and EVOO | Positive: Vegetables; dishes with tomato sauce (tomato, garlic, onion, leek, olive oil); pulses; nuts; fish; white meat over red meat; olive oil; olive oil as principal cooking fat.; Negative: Commercial pastries; red meat or sausages; animal fat; SSB; Alcohol and fruit (including juice) components excluded
Van Horn, 2018^39^ | DASH-style | Positive: Vegetables (not potatoes); nuts and legumes; fruit (including fruit juice); whole grains; low-fat dairy; Negative: Red and processed meat; sweetened beverages; sodium
Zhao, 2022^40^ | Mediterranean-style w/ recommended additional pistachios and EVOO | Positive: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; Negative: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries
Index/Score Analysis
Chia, 2018^4^ | Healthy Eating Index-2010 | Positive: Total fruit (including 100% juice); Whole fruit; Total vegetables (excluding starchy vegetables); Dark green leafy and orange vegetables; Total rice and alternatives (including products made from flour and starchy tuber vegetables); Whole grains; Dairy (including fortified soy beverages); Total protein foods (excluding dairy); Use of antenatal supplements containing iron, folate, and calcium; Negative: Total Fat; Total Saturated Fat
Fulay, 2018^7^ | DASH | Positive: fruit (including fruit juice); vegetables (not potatoes); whole grains; nuts/legumes; low-fat dairy; Negative: sodium; SSB; red and/or processed meats
| DASH OMNI | Positive: Fruit (including fruit juice); vegetables (not potatoes); whole grains; nuts/legumes; low-fat dairy; MUFA and PUFA; Negative: Sodium; SSB; red and/or processed meats
Haugen, 2008^9^ | Mediterranean Diet Index | Positive: Vegetables; fruits; fish; olive/canola, rapeseed oil; Negative: Meat; coffee
Hillesund, 2014^11^ | New Nordic Diet | Positive: ≥24 main meals/wk; Nordic fruits ≥5 times/wk; root vegetables ≥5 times/wk; cabbage ≥2 times/wk; potatoes ≥one-third of total occasions of eating potatoes, rice or pasta; choosing whole grain bread more often than refined bread; (vii) oatmeal ≥monthly; fish/game/berries about 2 times/wk; milk more often than juice; and ≥6 times as much water as SSB
Hillesund, 2018^10^ | Norwegian Fit For Delivery | Positive: regular meals; drinking water when thirsty; vegetables w/ dinner; fruits and vegetables between meals; reading nutrition labels before buying; Negative: sweets and snacks without appreciation; large portion sizes of unhealthy foods; added sugar; salt; eating beyond satiety
Li, 2021^14^; Yisahak, 2021^29^ | Alternative Healthy Eating Index-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA; Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Sodium; Alcohol and trans-fat components excluded
| Alternate Mediterranean Diet | Positive: Vegetables; Fruit; Nuts; Fish; Lean Meat (poultry, lean beef); Negative: Red and Processed Meat; Sodium.; Neutral: Grains and Starches; Dairy Foods; Alcohol component excluded
| DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy; Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Makarem, 2022^16^ | Alternate Mediterranean Diet | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA:SFA; Negative: Red and Processed Meat; Moderate: Alcohol
Martin, 2015^18^ | DASH | Positive: Fruits, vegetables, nuts and legumes, low-fat dairy, and whole grains; Negative: Sodium, red and processed meats, and sweetened beverages
Mikkelsen, 2008^20^ | Mediterranean diet | Positive: Vegetables; fruits; fish; olive or rapeseed oil; Negative: Meat; coffee
Navarro, 2019^22^ | Healthy Eating Index-2015 | Positive: Total fruits; whole fruits; total vegetables; greens and beans; total protein containing foods; seafood and plant proteins; whole grains; dairy; ratio of PUFA and MUFA to SFA; Negative: Refined grains; sodium; added sugars; SFA
Parisi, 2020^24^ | FIGO | Positive: Meat, fruit and vegetables, fish, dairy products, whole cereals, hemoglobin concentration, folic acid supplementation, iodized salt, sun exposure; Negative: Sweets and snacks
Robinson, 2021^26^ | Alternative Healthy Eating Index-2020 | Positive: Vegetables; fruit; whole grains; nuts and legumes; long-chain (omega-3) fats (EPA+DHA); PUFA; Negative: SSB and fruit juice; red/processed meat; trans fat; sodium; Moderate intake of alcohol
Yee, 2020^28^ | Healthy Eating Index-2010 | Positive: Total vegetables; greens and beans; total fruit (including juice); whole fruit; whole grains; seafood and plant proteins; total protein foods; dairy; fatty acids; Negative: Refined grains; empty calories (i.e., energy from solid fats, alcohol, and added sugars); sodium
Zhu, 2021^30^ | Alternative Healthy Eating Index-Pregnancy | Positive: Vegetables; whole fruit; whole grains; nuts and legumes; long-chain omega-3 fats (EPA+DHA); PUFA; calcium; folate; iron.; Negative: SSB; red/processed meat; trans fat; sodium
Factor/Cluster Analysis
Bodnar, 2024^2^ | High fruits, vegetables, whole grains, and plant proteins | Higher intake of vegetable medley/other vegetables, apples/pears, tomatoes, lettuce, broccoli, bananas, spinach/greens, strawberries/other berries, avocado, citrus fruits, tofu/meat substitutes, peaches/plums/ apricots/nectarines, yogurt, salad dressing, peas/string beans, nuts/seeds/nut or seed mixed dishes, sweet potatoes, other fruit/fruit salad, melon, coffee
| Sandwiches and snacks | Higher intake of coffee, alcoholic beverages, whole wheat bread, cold cuts, skim milk, diet soda/diet fruit drinks, pretzels/fat-free crackers/rice cakes, nuts/seeds/nut or seed mixed dishes, condiments, salad dressing, cream, unfried chicken or turkey/mixed dishes, crackers, reduced fat cheese, jam/jelly, white breads, sugars/honey, regular cheese, mayonnaise, nondairy creamer/cream substitutes
| Beverages, refined grains, and mixed dishes | Higher intake of reduced fat milk, 100% juice (not orange or grapefruit), rice/rice mixed dishes, 100% orange or grapefruit juice, Mexican mixed dishes, dried beans, soup, liver/other organ meats, whole milk, cold cereals, hot cereal, oils, vegetable juice, other white potatoes, vegetable mixed dishes, other meat/other meat mixed dishes, syrups/toppings, eggs/egg mixed dishes, pancakes/waffles/French toast/Pop Tarts, coleslaw
| High fat, sugar, and sodium | Higher intake of regular soda, fried chicken or fried turkey, fried white potatoes, burgers, sausage/franks/bacon/ribs, fruit drinks, chips/popcorn/other salty snacks, candy, pizza, grain desserts, other meat/other meat mixed dishes, white yeast breads, pancakes/waffles/French toast/Pop Tarts, dairy desserts, margarine, quick breads, beef/beef mixed dishes, crackers, other white potatoes, mayonnaise
Chia, 2016^3^ | Vegetable, fruit, and white rice | Higher intake of vegetables, fruits, plain white rice, whole-grain bread, fish, and nuts and seeds; Lower intakes of fried potatoes, burgers, carbonated and sweetened drinks, and flavored rice
Chia, 2016^3^ | Seafood and noodle | Higher intake of soup, seafood, fish and seafood products, noodles (flavored and in soup), and low-fat red meat; Lower intakes of legumes, ethnic bread, white rice, and curry-based gravies
| Pasta, cheese, and processed meat | Higher intake of pasta-, tomato-, and cream-based gravies, cheese, and processed meat
de Seymour, 2022^5^ | Fish, poultry and vegetables-based | Higher intake of fish; poultry; legumes and bean products; green leafy vegetables; root vegetables; other vegetables; seafood; fruits; eggs; organ meats; beverages; bread; dairy; soup; nuts
| Pasta, sweetened beverages, oils and condiments-based | Higher intake of pasta; sweetened beverages; oils and condiments; fast food
Englund-Ögge, 2014^6^ | Prudent pattern | Higher intake of raw and cooked vegetables, salad, onion/leek/garlic, fruit and berries, nuts, vegetables oils, water as beverage, whole grain cereals, poultry, and fibre rich bread; Lower intake of processed meat products (hot dogs, hamburgers, and so on), white bread, and pizza/tacos
| Western pattern | Higher intake of salty snacks, chocolate and sweets, cakes, French fries, white bread, ketchup, sugar sweetened drinks, processed meat products, and pasta; Lower intake of lean fish and fibre rich bread
| Traditional pattern | Higher intake of boiled potatoes, fish products, gravy, lean fish, margarine, rice pudding, low fat milk, and cooked vegetables; Lower intake of poultry and pizza/tacos
Grieger, 2014^8^ | High-protein/fruit | Higher intake of fish, meat, chicken, fruit, whole grains
| High-fat/sugar/takeaway | Higher intake of takeaway foods, potato chips, refined grains, added sugar
| Vegetarian-type | Higher intake of vegetables, whole grains, legumes
Hu, 2023^12^ | Fish-seafood | Higher intake of freshwater fish, marine fish, shrimps, crabs, mussels, seaweed, poultry, and organ Fish-seafood DP: Higher intake of freshwater fish, marine fish, shrimps, crabs, mussels, seaweed, poultry, and organ meats in TM1, TM2, & TM3; Additionally in TM1 and TM3 only: beef and lamb; Additionally in TM3 only: tubers
| Dairy-egg | Higher intake of dairy products, milk, eggs, egg products, beans, bean products, and nuts in TM1, TM2, & TM3
| Meat-staple | Higher intake of pork, poultry, beef, lamb, organ meats, tubers, and rice in TM2 & TM3; Also in TM3: wheat flour and products
| Fruit–vegetable | Higher intake of fruits, vegetables, beans, and bean products in TM1
Lu, 2018^15^ | Varied | Higher intake of mixed foods, including noodles, bread, root vegetables, melon vegetables, mushrooms, sea vegetables, bean vegetables, processed vegetables, poultry, animal organ meat, fish, other seafood, bean products, yoghurt, sweet beverages, puffed food, confectioneries, and snacks
| Milk | Higher intake of milk products (including fresh milk, pasteurized milk, milk powder, and formula for pregnant women) and lower intakes of whole vegetables
| Cereals, eggs, and Cantonese soups | Higher intake of rice, pasta, porridge, eggs, and Cantonese soups
| Meats | Higher intake of red and processed meat
| Fruits, nuts, and Cantonese desserts | Higher intake of fruits, nuts, and Cantonese desserts
| Vegetables | Higher intake of leafy and cruciferous vegetables
| Rich | Higher intake of grains, vegetables, poultry, animal organ meat, eggs, fish, other seafood, bean products, nuts, yoghurt, confectioneries, and snacks
| Milk-S | Higher intake of milk
| Fruits | Higher intake of fruits, sweet beverages, Cantonese desserts, and puffed food
| Meats-S | Higher intake of red meat, processed meat, and Cantonese soups
| Prudent | Lower intakes of all food groups, including cereals, vegetables and fruits, meats, eggs, fish, other seafood, bean products, nuts, milk, yoghurt, sweet beverages, Cantonese desserts, Cantonese soups, puffed food, confectioneries, snacks
Maldonado, 2022^17^ | Solid fat, refined grain, and cheese | Higher intake of milk, cheese, fruit juices, tomatoes, other vegetables, white potatoes, legumes, seafood, refined grains, meat, processed meats, poultry, eggs, soy protein, nuts and seeds, oils, solid fats, added sugar; Lower intake of yogurt, citrus, melons, berries, other fruits, dark green vegetables, other red and orange vegetables, other starchy vegetables, whole grains
Maldonado, 2022^17^ | Vegetables, oils, and fruit | Higher intake of milk, yogurt, cheese, citrus, melons, berries, other fruits, fruit juices, dark green vegetables, tomatoes, other red and orange vegetables, other vegetables, white potatoes, other starchy vegetables, legumes, seafood, whole grains, meat, processed meats, poultry, eggs, soy protein, nuts and seeds, oils, added sugar; Lower intake of refined grains, solid fats
Martin, 2015^18^ | Factor 1 | Higher intake of fruits, tomatoes, broccoli, spinach, carrots, green salads, sweet potatoes, low-fat milk, yogurt, high-fiber and highly fortified cereals, nonfried chicken and fish, and wheat bread
| Factor 2 | Higher intake of beans, corn, French fries, hamburgers or cheeseburgers, white potatoes, fried chicken, spaghetti dishes, cheese dishes such as macaroni and cheese, cornbread or hushpuppies, processed meats, biscuits, and ice cream
| Factor 3 | Higher intake of collard greens, coleslaw or cabbage, red meats, fried chicken and fish, processed meats, cornbread or hushpuppies, eggs or egg biscuits, gravy, whole milk, and vitamin C–rich drinks such as Kool-Aid and Hi-C
| Factor 4 | Higher intake of shellfish, pizza, salty snacks, candies, pancakes, tacos or burritos, and cakes and cookies
Miele, 2021^19^ | Obesogenic | Higher intake of ultra-processed and processed foods using NOVA classification (refined carbohydrate; fats; sweets)
| Intermediate | Lower intake of same food groups as “Obesogenic” DP
| Vegetarian | Higher intake of dairy, fruits, vegetables
| Protein | Higher intake of fatty meats, eggs, beans, very low intake of natural foods (using NOVA classification)
| Traditional | Higher intake of beans, meats, eggs, natural or minimally processed foods (using NOVA classification)
Mitku, 2020^21^ | Energy foods and snacks | Higher intake of energy bars, energy drinks, ice cream, chocolate, drinking yogurt, milk drinks, milkshake, fruit salad, cheese sauce, cheese, chicken with skin, chips, cold meat, red meat, flame-grilled fast-food chicken, hot dogs, sausages, fizzy soft drinks, fruit juice, hamburgers, pizza, rusks; Lower intake of cooking oil
| Spreads and fast foods | Higher intake of dripping, salad dressing low fat, fat holsum, schnitzels, skimmed, chocolate spread, bunny chow, venison, fizzy diet soft drinks, fish steamed, whole wheat, dried fruit, red meat fat removed, cookies, fried fast food chicken, pasta, organ meat, nuts and peanuts, pizza, pies and sausage rolls, vetkoek, rusks, hot dogs, butter; Lower intake of fizzy soft drinks
| Butter, junk foods, and juices | Higher intake of butter, sweets, muffins, chips, mixed salad, fruit juice, fresh fruit, fizzy soft drinks, vetkoek, coffee creamer, cooking oil, hamburgers, cooked vegetables, cereals rice crispies; Lower intake of soft margarine
| Protein-rich foods | Higher intake of fried fish, fish tinned, fried fish in fat, eggs cooked or poached, white brown bread, potato chips, chicken with skin; Lower intake of chicken without skin, red meat fat removed
| Starch foods | Higher intake of potato, breakfast cereals, potato with fat, legumes, full cream, cooked vegetables, cheese sauce, pasta, jam
| Nuts and rice foods | Higher intake of peanut butter, nuts and peanuts, rice mealie rice
| Vegetable-rich foods | Higher intake of vegetables, organ meat; Lower intake of butter
Paknahad, 2019^23^ | High Carbohydrate-Lower Fat | Higher intake of potato; fried potato; flour; egg; cooked carrots; pickles; noodle soup; beans; pomegranate; corn and maize; lentils; low-fat milk; lettuce; and raw carrot
| High Carbohydrate-Higher Fat | Higher intake of pea; soybean; fish; cabbage; cooked spinach; vegetable; high-fat milk; butter; tomato; cucumber; soup; cooked beans; and diluted yogurt
| High fiber | Higher intake of cantaloupe; melon; peach; nectarine; green tomatoes; plums; watermelons; pears; apricots
Rasmussen, 2014^25^ | Prudent | Higher intake of vegetables, fruit, legumes, fish, poultry, eggs, salad dressing, whole grains
| Alcohol | Higher intake of soya, root, berries, wine, liquor, and beer
| Vegetable/Prudent | Higher intake of cabbage, onion, mushroom, corn, salad, tomato, root, other vegetables, legumes, other fruit
| Western | Higher intake of potatoes, French fries, bread white, pork, beef veal, meat mixed, cold meat, dressing sauce, butter, margarine
| Seafood | Higher intake of fish, beef/veal and lamb, oil, egg, fermented milk, yogurt, Asian vegetables, other vegetables, tomato, onion
| Nordic | Higher intake of dark bread, Nordic fruit, hard cheese, banana, dried fruit, sweet spread
| Sweets | Higher intake of white bread, margarine, snack, sugar cakes, sweet spread, candy, dairy dessert, and chocolate
| Rice/Pasta/Poultry | Higher intake of ice, pasta, and poultry
Wang, 2021^27^ | Animal Food | Higher intake of fish, poultry, livestock
| Vegetarian | Higher intake of fruits, potatoes and their products, cereals and their products, vegetables, thallophytes, salted products, beans and their products, nuts
| Dairy and Egg | Higher intake of dairy products, eggs
Yisahak, 2021^29^ | PCA 1 | Higher intake of solid fat, nonwhole grains, white potatoes, meat (from beef, pork, veal, lamb, and game), cheese
| PCA 2 | Higher intake of other vegetables (not potatoes, starchy, orange, or dark-green vegetables), dark-green vegetables, orange vegetables, seafood high in omega-3 fatty acids, seafood low in omega-3 fatty acids
Reduced Rank Regression
Alves-Santos, 2019^1^ | Fast Food and Candies | Higher intake of fast food and snacks; cakes, cookies, or crackers; and candies or desserts; Lower intake of rice, beans, vegetables spices, and green vegetables or legumes
| Vegetables and Dairy | Higher intake of green vegetables or legumes, dairy products, fish, tea, fruits or fruit juices, and candies or desserts; low intakes of bread, sweetened and diet soda, and table sugar
| Beans, Bread, and Fat | Higher intake of beans; cakes, or cookies, or crackers; bread and fats used as spreads; Lower intake of fish, fruit or fruit juices, and noodles, pasta, roots, or tubers
Lecorguillé, 2020^13^ | Varied and balanced | Higher intake of low-fat milk, other vegetables, fish, meat, chicory, leek, cabbage, eggs and egg dishes, cereals, broccoli, liver; Lower intake of snacks and confectionary, SSB
| Vegetarian tendency | Higher intake of other vegetables, chicory, cereals, fruits, bread; Lower intake of meat, liver
| Bread and starchy food | Higher intake of bread, rice, pasta, and others, sandwich; Lower intake of low-fat milk, fruits, fruit juice, SSB

### Timing of exposure assessment

Thirty percent of articles assessed dietary patterns during the first trimester of pregnancy,^1,2,5,7,8,14,16,23,24,26,28–30^ 25% assessed diet during the second trimester,^6,9–11,13,15,19,20,22,25^, and 5% during the third trimester.^17,21^ Another four articles reported a single dietary assessment at any time during pregnancy.^3,4,18,22,27^ The remaining 11 articles, including all of the trials, conducted multiple dietary assessments across at least 2 trimesters.^12,31–40^

### Outcome

#### Preterm birth

All 40 articles reported preterm birth (i.e., delivery before 37 gestational weeks (GW)) as the outcome. Nine articles reported spontaneous preterm birth^2,3,6,11,12,15,16,18,24^ and 6 reported iatrogenic (i.e., induced or medically indicated) preterm birth.^3,6,12,15,16,18^ Ten articles reported early preterm birth, defined as delivery before 35 GW,^9,20^ before 34 GW,^6,15,21,31,32^ or before 32 GW.^6,25,36^ Late preterm birth was reported in 6 articles and defined as delivery ≥34 to <37 GW^2,6,15,21^ or ≥35 to <37 GW.^2,6,15,21^

## Synthesis of the Evidence

Eighty-three dietary patterns from 25 unique trials or cohorts reported in 35 articles^1–9,11–23,25–29,31–36,38,39^ were not significantly associated with risk of preterm birth.

Twenty-four dietary patterns from 19 articles (18 unique trials or cohorts) were associated with lower risk of preterm birth.^1,3,6,8,10,12–15,17,18,20,21,24,25,30,32,37,40^ Although the foods and food groups varied between dietary patterns, there was somewhat consistent evidence that these dietary patterns were characterized by higher intakes of vegetables, fruits, legumes, nuts and seeds, whole grains, fish/seafood, and unsaturated fats; as well as lower intakes of red and processed meat, added sugars, and saturated fats.

Thirteen dietary patterns from 8 cohorts^8,12,15,18,19,25–27^ were associated with greater risk of preterm birth. Foods and food groups included in these dietary patterns were mixed and tended to be characterized by higher intakes of vegetables, red and processed meat, dairy products (including high-fat dairy), and added sugars.

A summary of the findings is included below. Additional details are presented in Table 7.

### Intervention Studies

Six trials reported no statistically significant association between dietary patterns and preterm birth.^31–36,38,39^ The direction of the results generally trended toward lower risk of preterm birth, but there were mixed findings within studies and some results trending toward higher risk of preterm birth.

Three trials randomized participants to a Mediterranean-style diet with study-provided extra virgin olive oil (EVOO) and nuts. The multicenter, U.K.-based ESTEEM RCT^31^ found a statistically non-significant trend toward lower risk of preterm birth (<37 GW) and early preterm birth (<34 GW) in the intervention group. The St. Carlos GDM Prevention Study RCT conducted in Spain included a comparison group randomized to a Mediterranean-style diet with restricted fat (i.e., lower Mediterranean diet alignment). In the full sample,^32^ results were statistically non-significant for preterm birth <34 GW, but trended toward lower risk in the intervention group. In a subgroup analysis that restricted participants to normo-glycemic participants^33^ the results trended toward lower risk in the intervention group, but the results were not statistically significant. Another subgroup analysis further restricting the sample to Hispanic women with normoglycemia at baseline^38^ also revealed a statistically non-significant trend toward lower risk in the intervention group. Additionally, Melero et al.^38^ compared outcomes in Hispanic participants from a non-randomized group, where the intervention was implemented in a “real world” setting, to the original trial control group. In this “real world” group, participants were recommended to consume EVOO and nuts but were not provided with these foods. The “real world” group had a higher, but statistically non-significant, incidence of preterm birth. The IMPACT BCN RCT,^34^ which was also conducted in Spain, randomized participants to dietary training and personalized advice to increase adherence to the Mediterranean diet. Results trended toward lower risk of preterm birth in the intervention group.

The U.S.-based MOMFIT RCT^39^ randomized participants with pre-pregnancy BMI ≥25 kg/m^2^ to a calorie-controlled, DASH-style diet plus lifestyle intervention or usual care. The intervention additionally included recommendations to avoid fish considered higher in mercury and to consume calcium-rich, vitamin D-enriched dairy or calcium-fortified non-dairy products. Notably, the primary outcome was gestational weight gain and the trial was not designed to investigate preterm birth. Fewer participants in the intervention group delivered before 37 GW, but the difference was not statistically significant.

The OPTIMISE RCT randomized participants to a lifestyle intervention, including dietary advice consistent with the Australian dietary standards or standard care.^35^ Participants in the intervention group were advised to increase fiber intake, consume at least 2 servings of fruit per day, five servings of vegetables per day, and 3 servings of dairy per day. Healthy Eating Index (HEI) scores were marginally different between groups at both follow-up points, which may indicate a deviation from the intended intervention. The results were statistically non-significant but trended toward higher risk in the intervention group.

The U.S.-based LIFT RCT randomized participants with BMI ≥25 kg/m^2^ to diet modification and increased physical activity, along with behavioral and social support strategies delivered in individual sessions by study counselors, focusing on gestational weight gain control.^36^ Participants in the control group were invited to attend group meetings once every 8 weeks through delivery. Results were mixed, but statistically non-significant.

Three trials found a beneficial effect of a dietary intervention on risk of preterm birth. The risk of birth <37 GW in the full sample of participants from the St. Carlos GDM Prevention Study RCT (described above) was lower in the intervention group versus the control group.^32^ Zhao et al. conducted an RCT that examined a Mediterranean-style diet intervention in China.^40^ The intervention group was encouraged to consume EVOO and roasted pistachios every day (but was not supplied with EVOO or nuts), while the control group was recommended to restrict dietary fat. In Khoury et al.,^37^ participants were randomized to a dietitian-encouraged, cholesterol-lowering diet or usual consumption of a Norwegian diet (specifically asked not to introduce more oils, low-fat meat, or dairy products than usual).

No trials found a statistically significant detrimental effect of the intervention on risk of preterm birth.

### Observational Studies

#### Studies that report null or unclear, statistically non-significant findings

Nineteen cohort studies reported dietary patterns that were not statistically significantly associated with risk of preterm birth. Four studies^2,6,7,26^ reported small effect sizes that suggest a null relationship between dietary patterns and risk of preterm birth. Sixteen cohort studies additionally reported at least one dietary pattern with a statistically non-significant association with unclear findings due to wide confidence intervals, either overall^5,8,9,14,15,22,23,27,29^ or among select subgroups,^1,3,11,12,16,20^ or inconsistent trends across adherence levels and/or subgroups.^11,12,14,16,18,22,29^ Notably, some results were difficult to interpret due to the heterogeneity in the combination of foods within the dietary pattern or comparing alignment of one dietary pattern with another, somewhat similar pattern.^1–3,13,15,17–19,21,25,27^ Finally, 2 studies reported insufficient data to interpret potential trends (e.g., only p-values reported).^25,27^ Most of these dietary patterns were assessed during the first or second trimester of pregnancy.

#### Studies that suggest an association between dietary patterns and lower risk of preterm birth

The following dietary patterns based on the following indices/scores were statistically significantly associated with lower risk of preterm birth: DASH,^14,18^ Mediterranean-style diets,^14,20^ FIGO,^24^ the Alternative Healthy Eating Index,^30^ and the Norwegian Fit for Delivery diet.^10^ These beneficial patterns were generally characterized by higher intakes of vegetables, fruits, whole grains, legumes, fish and seafood, nuts and seeds, and unsaturated fats; and lower intakes of red and processed meat, added sugars, and sodium.

Several dietary patterns derived via factor or cluster analysis were statistically significantly associated with lower risk of preterm birth: ‘Vegetables, oils, fruit’ pattern,^17^ ‘Prudent’ pattern,^6^ ‘Vegetable, fruit, white rice’ pattern,^3^ ‘Rich’ pattern,^15^ ‘High protein, fruit’ pattern,^8^ ‘Fish-seafood’ pattern,^12^ ‘Seafood pattern’ pattern,^25^ ‘Nuts and rice foods’ pattern,^21^ ‘Vegetable-rich foods’ pattern,^21^ ‘Traditional’ pattern,^6^ ‘Vegetables’ pattern,^15^ ‘Starch foods’ pattern.^21^ These beneficial patterns were generally characterized by higher intakes of vegetables, grains/whole grains, red/processed meat, and fish/seafood, but other food groups varied between studies or were not specifically reported as part of the dietary patterns.

Two reduced rank regression-derived dietary patterns were associated with lower risk of preterm birth. In one study from Brazil,^1^ the ‘Vegetables and Dairy’ pattern was associated with lower risk of preterm birth among those with the highest versus lowest adherence; medium versus lowest adherence was not statistically significant but also trended toward lower risk. In another study from France,^13^ the ‘Vegetarian tendency’ pattern was associated with lower risk of preterm birth.

Several dietary patterns trended toward lower risk of preterm birth but none of the estimated effects were statistically significant. When these patterns were derived from indices or scores,^4,28,29^ the patterns were generally characterized by higher intakes of vegetables, fruits, whole grains, legumes, nuts and seeds, and unsaturated fats and lower intakes of red/processed meat, added sugars, and sodium. Food components were less consistent when patterns were derived via factor or cluster analysis,^3,6,29^ but often included higher intakes of vegetables, fruits, grains/whole grains, legumes (especially beans), and nuts and seeds, and sometimes included higher intakes of meats (white/lean and red/processed), fish/seafood, or dairy.

These dietary patterns that suggested an association with lower risk of preterm birth were not assessed at a consistent time during pregnancy.

#### Studies that suggest an association between dietary patterns and higher risk of preterm birth

No dietary patterns derived from indices/scores or reduced rank regression were statistically significantly associated with higher risk of preterm birth. Twelve dietary patterns derived from factor/cluster analysis in 7 cohorts were associated with higher risk of preterm birth: a ‘High-fat/sugar/takeaway’ pattern^8^; the ‘Dairy-egg’ and ‘Fish-seafood’ patterns from Hu et al.^12^; the ‘Milk’ pattern (derived using percentages), ‘Milk-S’ pattern (derived using frequencies), ‘Fruits, nuts, and Cantonese desserts’ pattern, and the ‘Cereals, eggs, Cantonese soups’ pattern from the Born in Guangzhou Cohort Study,^15^; ‘Factor 2’ and ‘Factor 3’ from the Pregnancy, Infection, and Nutrition study^18^; a ‘Protein’ pattern^19^; a ‘Western’ pattern^25^; and an ‘Animal food’ pattern.^27^ The foods and food groups across these patterns varied widely, although beans, fried foods, and red/processed meats were somewhat common in the patterns. Three additional dietary patterns included higher intakes of French fries, refined grains, processed meats, and added sugars and reported statistically non-significant trends toward higher risk of preterm birth.^5,6,19^ Another study^13^ reported a statistically non-significant association that trended toward higher risk of preterm birth. This dietary pattern was higher in vegetables, grains, meat (including red meat), fish, eggs, low-fat dairy, and chicory, and lower in added sugars and snacks. Most of these dietary patterns were assessed during the second or third trimester of pregnancy.

## Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between dietary patterns consumed during pregnancy and gestational age?” based on their review of the body evidence (Table 6).

Table 6 Conclusion statement, grade for dietary patterns consumed during pregnancy and preterm birth

Conclusion Statement | Dietary patterns consumed during pregnancy may not be associated with risk of preterm birth. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 40 articles: 22 PCS, 8 RCT, 1 NRCT
Consistency | Results were somewhat inconsistent in direction and magnitude of effect across significant and nonsignificant results. Some of the inconsistencies could be explained by methodological differences.
Precision | The body of evidence had concerns due to precision, with some studies demonstrating sufficient power, as well as wide variance around the effect estimates.
Risk of bias | Most studies had overall high risk of bias due to confounding, deviations from intended interventions, post-exposure interventions, missing data, and selective reporting of the results.
Directness | The body of evidence had substantial concerns with directness. Majority of studies were not designed to directly examine the relationship between dietary patterns and risk of preterm birth.
Generalizability | Limited generalizability to the U.S. population when considering country, socioeconomic position, and dietary patterns studied. Among studies in the U.S., there was some racial and ethnic diversity.

### Assessment of the evidence

The body of evidence included 40 articles from 22 PCS, 8 RCT, and one NRCT (see Table 6). Some of the limitations in the evidence may relate to the outcome. Preterm birth is complex and multifactorial; therefore, if an association between diet and risk of preterm birth exists, it may be of a smaller magnitude than other causes and thus may be challenging to detect.

The body of evidence was also limited by challenges that are specific to conducting research in pregnant populations. For example, dietary assessments during early pregnancy can be affected by the timely awareness of pregnancy and by variation in diet related to nausea and vomiting of pregnancy. Additionally, the finite length of pregnancy limits the duration between the dietary intake assessment and the outcome assessment at birth and can thus limit both the potential for diet to impact pregnancy outcomes and the potential for researchers to adequately assess the hypothesized relationship. Finally, there was wide variation in dietary patterns studied and in the composition of those dietary patterns.

Publication bias is always a concern and while the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias in this systematic review. However, this body of evidence included articles with both large and small sample sizes, as well as statistically significant and null findings, so publication bias may be less likely.

#### Consistency

There was moderate consistency in the direction and magnitude of effect across trials; most of the results suggested a null or beneficial association, but there was some inconsistency in the magnitude of effect. Most trials examined a Mediterranean-style diet, and thus there was little variation in the individual foods and food groups consumed. Some of the inconsistencies in findings could be explained by methodological differences, such as small sample sizes, deviations from the intended interventions, and lack of trials designed to assess the relationship between dietary patterns and risk of preterm birth.

The direction of effect across statistically significant and non-significant results showed limited consistency in observational study articles. Additionally, wide variation in the magnitude of effect, the timing of dietary assessment, and the composition of the dietary patterns contributed to inconsistency of the cohort studies; few inconsistencies in the findings could be explained by methodological differences.

#### Precision

Few sufficiently powered intervention studies were included in the body of evidence. Results had wide confidence intervals and none of the articles reported sufficient power to detect differences in risk of preterm birth. One trial reported an insufficient sample size for detecting a difference in gestational weight gain and another reported a sufficient sample size to detect differences in GDM but did not report the magnitude of the difference that could be detected. Two trials reported <80% power to detect differences in non-preterm birth outcomes. The remaining trials reported sufficient sample sizes for a different pregnancy or neonatal outcome.

A sufficient number of observational studies should have had sample sizes large enough to detect differences in preterm birth rates, although some subgroup analyses were quite small. However, there may have been an insufficient number of cases in some studies; wide confidence intervals were also a concern in this body of evidence.

#### Risk of bias

Four articles from 2 trials had overall high risk of bias due to concerns about deviations from intended interventions. These concerns arose because more participants in one group were diagnosed with GDM and preterm birth is necessarily assessed post-GDM diagnosis. If participants diagnosed with GDM were treated with dietary changes or insulin and GDM rates differed between the intervention and control groups, this could have affected outcomes later in pregnancy, including the risk of preterm birth and other predictors of preterm birth. There was also some concern about risk of bias due to selective reporting of the results for most of the interventions. This was generally due to a lack of a pre-specified analysis plan or no strong justification for secondary analyses that were not specified in the original protocol and that only included a subset of participants. Domain-specific ratings of risk of bias for intervention studies are displayed in Table 8 and Table 9.

Risk of bias domain ratings for observational study articles are presented in Table 10. Most observational study articles had concerns for risk of bias due to confounding, post-exposure interventions, missing data, and selective reporting of the results. Few cohort studies accounted for all key confounders without controlling for post-exposure variables (e.g., gestational weight gain). Many studies had concerns related to post-exposure interventions because they did not report on rates of GDM between groups. As described above for trials, differential GDM diagnoses between exposure groups could result in different GDM treatments (e.g., dietary changes) that could subsequently impact the risk of preterm birth. Most articles also reported inadequate information on missing data or, when they reported missing data, did not perform appropriate analyses to prove the results were not biased by missing data. As in the intervention studies, risk of bias due to selection of the reported results was a concern because no cohort studies included dietary patterns and risk of preterm birth in a pre-specified analysis plan. Additionally, some of the cohorts had concerns of bias due to exposure assessment methods when the diet assessment was not validated in a pregnant population or if the measured exposure did not well characterize a dietary pattern (i.e., only including a few food groups).

#### Directness

None of the trials were directly designed to examine the relationship between dietary patterns and preterm birth. All trials were designed to examine the effect of a dietary intervention on pregnancy (e.g., GDM, blood lipids, appropriate gestational weight gain) or neonatal outcomes (e.g., small for gestational age, macrosomia). Some of the trials included lifestyle or exercise interventions in addition to dietary advice, although physical activity did not differ between groups over time. A few trials provided nuts and EVOO, which may have explained most of the difference in Mediterranean-style diet scores.

Most of the cohort studies were designed to examine pregnancy outcomes, but preterm birth was not a primary outcome. Further, although diet was an isolated exposure in all the included analyses, most cohorts were designed to examine multiple exposures; few studies focused on diet as the primary exposure.

#### Generalizability

Only 2 trials were conducted in the U.S., and these had the smallest sample sizes of all the trials. Although less than half of the trials reported on education, those that did stated that most participants had at least some university education. When reported, most trials described samples as having majority employed, with “middle” class income or high socioeconomic status, and with pre-pregnancy normal BMI. Race and/or ethnicity of participants was somewhat mixed across trials. The prevalence of preterm birth was generally 6-7%, lower than the U.S. average (approximately 10%^*^).

* Martin JA, Hamilton BE, Osterman MJK. Births in the United States, 2023. NCHS Data Brief, no 507. Hyattsville, MD: National Center for Health Statistics. 2024. DOI: 10.15620/cdc/158789.

Ten articles from 6 unique cohorts were conducted in the U.S. Most studies reported that the majority of participants were relatively highly educated, employed, and with at least “middle” income levels. While many observational study articles did not report race and/or ethnicity, of those that did, there was some diversity, especially in the articles from the U.S. However, no articles reported American Indian or Alaska Native participants and there was limited generalizability when considering pre-pregnancy BMI. The prevalence of preterm birth was generally ≤10%.