# Plain language summary

### What is the question?

The question is: What is the relationship between dietary patterns consumed during pregnancy and gestational age at birth? The populations of interest for this question include individuals during pregnancy and infants at birth.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team. This review updated an existing review that was conducted as part of the Pregnancy and Birth to 24 Months Project.

### What is the answer to the question?

Dietary patterns consumed during pregnancy may not be associated with risk of preterm birth. This conclusion statement is based on evidence graded as limited.

### How up-to-date is this systematic review?

The conclusion statement from this review is based on articles published between January 1980 and January 2024.