# Appendix 6 Dietary pattern visualization

The Committee’s synthesis was facilitated by a data visualization table that presented the dietary pattern components in each of the dietary patterns examined in the body of evidence (Table A 9). During evidence synthesis, these tables were used in conjunction with other materials to compare and contrast the components in the dietary patterns studied along with the direction, magnitude, and statistical significance of reported results. Detailed information about the synthesized body of evidence, including study and population characteristics, reported results for all relevant outcomes, key confounders accounted for, and funding sources, are summarized in the evidence tables of this report (Table 5, Table 7).

Each column represents the most commonly reported foods/food groups or nutrients across dietary patterns in this body of evidence. Two additional columns, “Other A” and “Other B”, captured a variety of other components less frequently reported across dietary patterns that did not fit into one of the preceding columns or categories, such as fast food, ready-to-eat dishes, and pizza. Empty cells mean that the dietary pattern did not include a component within that column/category.

Table A 9 Visualization of dietary pattern components organized by approach across evidence examining the relationship between dietary patterns consumed during pregnancy and gestational age at birth^*^ * ▲ Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as part of the pattern; ◄ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern. ^†^ † Abbreviations: AS: added sugar; C: coffee; Ca: calcium; Fe: iron; Fr: included with Fruit component; F: fish; FA: fatty acids; MUFA: monounsaturated fatty acids; M: meat and/or meat products; N: nuts; NRCT: non-randomized controlled trial; OO: olive oil; P: processed meat; pro: protein; PUFA: polyunsaturated fatty acids; R: red meat; RCT: randomized controlled trial; S: seafood; SFA: saturated fatty acids; T: tea; W:R: ratio of white to red meat

Article; Dietary Pattern | Vegetables | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains | Grains: Whole | Grains: Refined | Fish, Seafood | Meats: Red, Processed | Meats: Lean, Poultry | Eggs | Dairy | Dairy: Low, Non-fat | Dairy: Whole, High-fat | SSB | Sugary Foods | Fats | Fats: Unsaturated, Oils | Fats: Saturated | Alcohol | Tea and Coffee | Sodium | Other Nutrients | Other A | Other B
RCT
Al Wattar, 2019;^31^ Mediterranean- (Med) style diet | ▲ | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | | ▲ OO | ▼
Assaf-Balut, 2017;^32^ Med w/ pistachios + EVOO | ▲ | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | | ▲ OO | ▼ | ▲
Assaf-Balut, 2019;^33^ Med w/ pistachios + EVOO | ▲ | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | | ▲ OO | ▼ | ▲
Crovetto, 2021;^34^ Med w/ walnuts + EVOO | ▲ | ▲ | ▲ | | ▲ N | | ▲ | ▼ | ▲ F | ▼ RP | ▲ | | ▲ | | | ▼ | ▼ | | ▲ OO | ▼
Dodd, 2019;^35^ Australian dietary standards | ▲ | | ▲ | | | | | | | | | | ▲
Gallagher, 2018;^36^ Lifestyle intervention w/ higher HEI-2010 | ▲ | ▲ pro | ▲ | Fr | pro | | ▲ | ▼ | ▲ S | pro | pro | pro | ▲ | | | ▼ AS | AS | | ▲ FA | ▼ | ▼ | | ▼
Khoury, 2005;^37^ Cholesterol-lowering diet advice | ▲ | | ▲ | | ▲ | | | | ▲ F | ▼ M | M | | | | ▼ | | | | ▲ | ▼ | | | | | ▲
Melero, 2020;^38^ Med w/ pistachios + EVOO | ▲ | ▲ | | | ▲ N | | | | ▲ F | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | | ▲ OO | ▼
Van Horn, 2018;^39^ Calorie-controlled, DASH-type diet | ▲ | ▲ | ▲ | Fr | ▲ N | | ▲ | | | ▼ RP | | | | ▲ | | ▼ | | | | | | | ▼
Zhao, 2022;^40^ Med w/ recommended pistachios + EVOO | ▲ | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | | ▲ OO | ▼ | ▲
NRCT
Melero, 2020;^38^ Med w/ pistachios + EVOO | ▲ | ▲ | | | ▲ N | | | | ▲ F | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | | ▲ OO | ▼
Index/Score (Reference)
Chia, 2018;^4^ HEI-SGP | ▲ | ▲ pro | ▲ | ▲ | | ▲ | ▲ | | pro | pro | pro | | ▲ | | | | | ▼ | | ▼ | | | | ▲ Ca, Fe, Folate
Fulay, 2018;^7^ DASH | ▲ | ▲ | ▲ | ▲ | ▲ N | | ▲ | | | ▼ RP | | | | ▲ | | ▼ | | | | | | | ▼
Fulay, 2018;^7^ DASH OMNI | ▲ | ▲ | ▲ | ▲ | ▲ N | | ▲ | | | ▼ RP | | | | ▲ | | ▼ | | | ▲ MUFA+ PUFA | | | | ▼
Haugen, 2008;^9^ Med-style | ▲ | | ▲ | | | | | | ▲ F | ▼ M | M | | | | | | | | ▲ | | | ▼ C
Hillesund, 2014;^11^ New Nordic Diet | ▲ | | ▲ | ▼ | | | ▲ | ▼ | ◄ F | ◄ | ◄ | | ▲ | | | ▼ | | | | | | | | | ▲
Hillesund, 2018;^10^ NFFD | ▲ | | ▲ | | | | | | | | | | | | | ▼ AS | AS | | | | | | ▼ | | ▲ | ▼
Li, 2021;^14^ AHEI | ▲ | ▲ | ▲ | ▼ | ▲ N | | ▲ | | | ▼ RP | | | | | | ▼ | | | ▲ PUFA | | | | ▼
Li, 2021;^14^ aMED | ▲ | | ▲ | | ▲ N | ◄ | | | ▲ F | ▼ RP | ▲ | | ◄ | | | | | | | | | | ▼
Li, 2021;^14^ DASH | ▲ | ▲ | ▲ | ▲ | ▲ N | | ▲ | | | ▼ RP | | | | ▲ | | ▼ | | | | | | | ▼
Makarem, 2022;^16^ aMed | ▲ | ▲ | ▲ | | ▲ N | | ▲ | | ▲ F | ▼ RP | | | | | | | | | ▲ MUFA: SFA | MUFA: SFA | ◄
Martin, 2015;^18^ DASH | ▲ | ▲ | ▲ | | ▲ N | | ▲ | | | ▼ RP | | | | ▲ | | ▼ | | | | | | | ▼
Mikkelsen, 2008;^20^ Med | ▲ | | ▲ | | | | | | ▲ F | ▼ M | M | | | | | | | | ▲ | | | ▼ C
Navarro, 2019;^22^ HEI-2015; | ▲ | ▲ | ▲ | Fr | | | ▲ | ▼ | ▲ S | ▲ PRO | PRO | | ▲ | | | ▼ AS | AS | | ▲ MUFA+ PUFA: SFA | ▼ SFA
Parisi, 2020;^24^ FIGO | ▲ | | ▲ | | | | ▲ | | ▲ F | ▲ M | M | | ▲ | | | | ▼ | | | | | | ▲ | ▲ Folic acid | ▲ | ▼
Robinson, 2021;^26^ AHEI-2010 | ▲ | ▲ | ▲ | ▼ | ▲ N | | ▲ | | | ▼ RP | | | | | | ▼ | | | ▲ PUFA | ▼ | ◄ | | ▼
Yee, 2020;^28^ HEI-2010 | ▲ | ▲ pro | ▲ | Fr | pro | | ▲ | ▼ | ▲ S | pro | pro | pro | ▲ | | | ▼ AS | AS | | ▲ FA | ▼ Solid | ▼ | | ▼
Yisahak, 2021;^29^ AHEI-2010 | ▲ | ▲ | ▲ | | ▲ N | | ▲ | | | ▼ RP | | | | | | ▼ | | | ▲ PUFA | ▼ | | | ▼
Yisahak, 2021;^29^ aMED | ▲ | ▲ | ▲ | | ▲ N | | ▲ | | ▲ F | ▼ RP | | | | | | | | | ▲ MUFA: SFA | MUFA: SFA
Yisahak, 2021;^29^ DASH | ▲ | ▲ | ▲ | | ▲ | | ▲ | | | ▼ RP | | | | ▲ | | ▼ | | | | | | | ▼
Zhu, 2021;^30^ AHEI-P | ▲ | ▲ | ▲ | | ▲ N | | ▲ | | | ▼ RP | | | | | | ▼ | | | ▲ PUFA | ▼ | | | ▼ | ▲ Ca, Fe, Folate
Factor/Cluster Analysis
Bodnar, 2023;^2^ Beverages, refined grains, and mixed dishes | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▲ | | ▲ | | ▲ | ▲ | ▲ AS | ▲ | | ▲ | | | | | | ▲
Bodnar, 2023;^2^ High fruits, vegetables, whole grains, and plant proteins | ▲ | ▲ | ▲ | | ▲ | | | | | | | | ▲ | | | | | ▲ | | | | ▲ C
Bodnar, 2023;^2^ Sandwiches and snacks | | | | | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | ▲ | ▲ AS | AS | ▲ | | ▲ | ▲ | ▲ C | | | ▲
Chia, 2016;^3^ Pasta, cheese, processed meat | ▲ | | | | | ▲ | | | | ▲ P | | | | | ▲
Chia, 2016;^3^ Seafood and noodle | | ▲ | | | | ◄ | | ▼ | ▲ | ▲ R | | | | | | | | | | | | | | | ▲ | ▼
Chia, 2016;^3^ Vegetable, fruit, white rice | ◄ | | ▲ | | ▲ | | ▲ | ◄ | ▲ F | ▲ R | | | | | | ▲
de Seymour, 2022;^5^ Fish, poultry, and vegetables-based | ▲ | ▲ | ▲ | | ▲ N | ▲ | | | ▲ | ▲ | ▲ | ▲ | ▲ | | | | | | | | | | | | ▲
de Seymour, 2022;^5^ Pasta, sweetened beverages, oils, and condiments-based | | | | | | ▲ | | | | | | | | | | ▲ | | ▲ | ▲ | | | | | | ▲
Englund-Ogge, 2014;^6^ Prudent | ▲ | | ▲ | | ▲ N | | ▲ | ▼ | | ▼ P | ▲ | | | | | | | | ▲ | | | | | | ▲ | ▼
Englund-Ogge, 2014;^6^ Traditional | ▲ | | | | | | | | ▲ F | | ▼ | | | ▲ | | | ▲ | | ▲ | ▲ | | | | | ▲ | ▼
Englund-Ogge, 2014;^6^ Western | ▲ | | | | | ▼ | ▼ | ▲ | ▼ F | ▲ P | | | | | | ▲ | ▲ | | | | | | ▲ | | ▲
Grieger, 2014;^8^ High protein, fruit | | | ▲ | | | | ▲ | | ▲ F | ▲ | ▲
Grieger, 2014;^8^ High-fat/sugar/ta keaway | | | | | | | | ▲ | | | | | | | | ▲ AS | AS | | | | | | | | ▲
Grieger, 2014;^8^ Vegetarian-type | ▲ | ▲ | | | | | ▲
Hu, 2023;^12^ Dairy-egg | ▲ | ▲ | | | ▲ N | | | | | | | ▲ | ▲
Hu, 2023;^12^ Fish-seafood | ▲ | | | | | | | | ▲ | ▲ R | ▲
Hu, 2023;^12^ Fruit-vegetable | ▲
Hu, 2023;^12^ Meat-staple | ▲ | | | | | ▲ | | | | ▲ M | M
Lu, 2018;^15^ Cereals, eggs, Cantonese soups | | | | | | ▲ | | | | | | ▲ | | | | | | | | | | | | | ▲
Lu, 2018;^15^ Fruits | | | ▲ | | | | | | | | | | | | | ▲ | ▲ | | | | | | | | ▲
Lu, 2018;^15^ Fruits, nuts, and Cantonese desserts | | | ▲ | | ▲ N | | | | | | | | | | | | ▲
Lu, 2018;^15^ Meats | | | | | | | | | | ▲ RP
Lu, 2018;^15^ Meats-S | | | | | | | | | | ▲ RP | | | | | | | | | | | | | | | ▲
Lu, 2018;^15^ Milk | ▲ | | | | | | | | | | | | ▲
Lu, 2018;^15^ Milk-S | | | | | | | | | | | | | ▲
Lu, 2018;^15^ Prudent | ▼ | ▼ | ▼ | | ▼ N | ▼ | | | ▼ | ▼ M | M | ▼ | ▼ | | | ▼ | ▼ | | | | | | | | ▼
Lu, 2018;^15^ Rich | ▲ | ▲ | | | ▲ N | ▲ | | | ▲ | ▲ | ▲ | ▲ | ▲ | | | | ▲ | | | | | | | | ▲
Lu, 2018;^15^ Varied | ▲ | ▲ | | | | ▲ | | | ▲ | ▲ | ▲ | | ▲ | | | ▲ | ▲ | | | | | | | | ▲
Lu, 2018;^15^ Vegetables | ▲
Maldonado, 2022;^17^ Solid fat, refined grain, cheese | ◄ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▲ | ▲ S | ▲ RP | ▲ | ▲ | ◄ | | | ▲ AS | AS | | ▲ | ▲ Solid
Maldonado, 2022;^17^ Vegetables, oils, fruit | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ | ▲ S | ▲ RP | ▲ | ▲ | ▲ | | | ▲ AS | AS | | ▲ | ▼ Solid
Martin, 2015;^18^ Factor 1 | ▲ | | ▲ | | | ▲ | ▲ | | ▲ F | | ▲ | | | ▲
Martin, 2015;^18^ Factor 2 | ▲ | | | | | ▲ | | | | ▲ RP | ▲ | | | | ▲ | | ▲
Martin, 2015;^18^ Factor 3 | ▲ | | | | | ▲ | | | ▲ F | ▲ RP | ▲ | ▲ | | | ▲ | ▲ | | | | | | | | | ▲
Martin, 2015;^18^ Factor 4 | | | | | | ▲ | | | ▲ S | | | | | | | | ▲ | | | | | | ▲ | | ▲
Miele, 2021;^19^ Intermediate | | | | | | | | ▼ | | | | | | | | | ▼ | ▼ | | | | | | | ▼
Miele, 2021;^19^ Obesogenic | | | | | | | | ▲ | | | | | | | | | ▲ | ▲ | | | | | | | ▲
Miele, 2021;^19^ Protein | ▲ | ▲ | | | | | | | | ▲ | | ▲ | | | | | | | | | | | | | ▼
Miele, 2021;^19^ Vegetarian | ▲ | | ▲ | | | | | | | | | | ▲
Mitku, 2020;^21^ Butter, junk foods, and juices | ▲ | | | ▲ | | ▲ | | ▲ | | ▲ R | | | | | | ▲ | ▲ | | ▼ | ▲ | | | | | ▲
Mitku, 2020;^21^ Energy foods and snacks | | | ▲ | ▲ | | | | ▲ | | ▲ RP | ▲ | | ▲ | ▲ | ▲ | ▲ | ▲ | ◄ | ▼ | | | | | | ▲
Mitku, 2020;^21^ Nuts and rice foods | | | | | ▲ N | ▲
Mitku, 2020;^21^ Protein-rich foods | | | | | | ▲ | | | ▲ F | ◄ | ◄ | ▲ | | | | | | ▲ | | ▲ | | | ▲
Mitku, 2020;^21^ Spreads and fast foods | | | ▲ | | ▲ N | | ▲ | ▲ | ▲ F | ▲ RP | ▲ | | | | | ▼ | ▲ | ▲ | | | | | | | ▲
Mitku, 2020;^21^ Starch foods | ▲ | ▲ | | | | ▲ | | | | | | | | | ▲ | | ▲
Mitku, 2020;^21^ Vegetable-rich foods | ▲ | | | | | | | | | ▲ | | | | | | | | | | ▼
Paknahad, 2019;^23^ High Carbohydrate-Higher Fat | ▲ | ▲ | | | | | | | ▲ F | | | | | | ▲ | | | | | ▲ | | | | | ▲
Paknahad, 2019;^23^ High Carbohydrate-Lower Fat | ▲ | ▲ | ▲ | | | ▲ | | | | | | ▲ | | ▲ | | | | | | | | | | | ▲
Rasmussen, 2014;^25^ Alcohol | ▲ | | | | | | | | | | | | | | | | | | | | ▲
Rasmussen, 2014;^25^ Nordic pattern | | | ▲ | | | ▲ | | | | | | | | | ▲ | | ▲
Rasmussen, 2014;^25^ Rice/Pasta/Poultry | | | | | | ▲ | | | | | ▲
Rasmussen, 2014;^25^ Seafood pattern | ▲ | | | | | | | | ▲ F | ▲ R | | ▲ | ▲ | | | | | | ▲
Rasmussen, 2014;^25^ Sweets pattern | | | | | | | | ▲ | | | | | | | | | ▲ | | ▲ | ▲ | | | | | ▲
Rasmussen, 2014;^25^ Vegetable/Prudent | ▲ | ▲ | ▲
Rasmussen, 2014;^25^ Western | ▲ | | | | | | | ▲ | | ▲ R | | | | | | | | | | | | | | | ▲
Wang, 2021;^27^ Animal food | | | | | | | | | ▲ F | ▲ | ▲
Wang, 2021;^27^ Dairy and Egg | | | | | | | | | | | | ▲ | ▲
Wang, 2021;^27^ Vegetarian | ▲ | ▲ | ▲ | | ▲ N | ▲ | | | | | | | | | | | | | | | | | ▲
Yisahak, 2021;^29^ Pattern 1 | ▲ | | | | | | | ▲ | | ▲ R | | | ▲
Yisahak, 2021;^29^ Pattern 2 | ▲ | | | | | | | | ▲ S
Other
Alves-Santos, 2019;^1^ Beans, Bread, and Fat | ◄ | ▲ | ▼ | ▼ | | ◄ | | | ▼ F | | | | | | | | ▲ | ▲
Alves-Santos, 2019;^1^ Fast Food and Candies | ▼ | ▼ | | | | ◄ | | | | | | | | | | | ▲ | | | | | | | | ▲ | ▼
Alves-Santos, 2019;^1^ Vegetables and Dairy | ▲ | ▲ | ▲ | ▲ | | ▼ | | | ▲ F | | | | ▲ | | | ▼ | ▲ | | | | | | | | ▼
Lecorguille, 2020;^13^ Bread, starchy food | | | ▼ | ▼ | | ▲ | | | | | | | | ▼ | | ▼ | | | | | | | | | ▲
Lecorguillé, 2020;^13^ Varied and balanced | ▲ | | | | | ▲ | | | ▲ F | ▼ M | M | ▲ | | ▲ | | ▼ | ▼ | | | | | | | | ▲ | ▼
Lecorguillé, 2020;^13^ Vegetarian tendency | ▲ | | ▲ | | | ▲ | | | | ▼ M | M | | | | | | | | | | | | | | ▲