# Appendix 5 Excluded articles

The existing systematic review^*^ for this question included 11 articles. However, after applying the inclusion and exclusion criteria established for the update to that review, only 9 remained eligible for inclusion. The following articles were excluded from the existing systematic review due to updated eligibility criteria:

1. Gresham E, Collins CE, Mishra GD, Byles JE, Hure AJ. Diet quality before or during pregnancy and the relationship with pregnancy and birth outcomes: the Australian Longitudinal Study on Women’s Health. Public Health Nutr. 2016;19(16):2975-83. (Excluded for: Life Stage)
2. Xie Y, Madkour AS, Harville EW. Preconception Nutrition, Physical Activity, and Birth Outcomes in Adolescent Girls. J Pediatr Adolesc Gynecol. 2015;28(6):471-6. (Exlcuded for: Outcome)

* Raghavan R, Dreibelbis C, Kingshipp BJ, Wong, YP, Terry N, Abrams B, Bartholomew A, Bodnar LM, Gernand A, Rasmussen K, Siega-Riz AM, Stang JS, Casavale KO, Spahn JM, Stoody E. Dietary Patterns before and during Pregnancy and Gestational Age at Birth: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0103.

The following tables list the articles excluded after full-text screening for the updated systematic review literature search (Appendix 4) Articles excluded from the search are in Table A 8. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 8 Articles excluded after full text screening

| Citation | Rationale
1 | Corrections. Chia A-R et al. A vegetable, fruit, and white rice dietary pattern during pregnancy is associated with a lower risk of preterm birth and larger birth size in a multiethnic Asian cohort: the Growing Up in Singapore Towards healthy Outcomes (GUSTO) cohort study. Am J Clin Nutr 2016. 104:1416–23. Am J Clin Nutr. 2018. 107:484-484. doi:10.1093/ajcn/nqx051. | Publication Status
2 | Abdelhamid ER, Kamhawy AH, Gad MA, et al. Association between maternal nutrition and fetal developmental profile: Do leptin and adiponectin have a significant role? Current Pediatric Research. 2021. 25:862-874 | Study Design; Intervention/Exposure
3 | Abdou RM, El Hawary GS, Saab AA. Effect of gestational Mediterranean diet intervention on newborn fat mass and cord blood leptin level. Egyptian Pediatric Association Gazette. 2020. 68. doi:10.1186/s43054-020-00042-y. | Country
4 | Abu-Saad K, Kaufman-Shriqui V, Freedman LS, et al. Preconceptional diet quality is associated with birth outcomes among low socioeconomic status minority women in a high-income country. Eur J Nutr. 2021. 60:65-77. doi:10.1007/s00394-020-02221-4. | Outcome
5 | Acosta-Manzano P, Acosta FM, Coll-Risco I, et al. The Influence of Exercise, Lifestyle Behavior Components, and Physical Fitness on Maternal Weight Gain, Postpartum Weight Retention, and Excessive Gestational Weight Gain. Int J Sport Nutr Exerc Metab. 2022 Jul 12:1-14. doi: 10.1123/ijsnem.2021-0201. | Outcome; Comparator
6 | Ainscough KM, Kennelly MA, Lindsay KL, et al. An observational analysis of meal patterns in overweight and obese pregnancy: exploring meal pattern behaviours and the association with maternal and fetal health measures. Ir J Med Sci. 2020. 189:585-594. doi:10.1007/s11845-01902099-0. | Intervention/Exposure
7 | Aji AS, Lipoeto NI, Yusrawati Y, et al. Impact of maternal dietary carbohydrate intake and vitamin D-related genetic risk score on birth length: the Vitamin D Pregnant Mother (VDPM) cohort study. BMC Pregnancy Childbirth. 2022 Sep 7. 22(1):690. doi: 10.1186/s12884-022-05020-3. | Intervention/Exposure
8 | Alamolhoda SH, Asghari G, Mirabi P. Does trans fatty acid affect low birth weight? A randomised controlled trial. J Obstet Gynaecol. 2022. 42:1-7. doi:10.1080/01443615.2022.2080532. | Intervention/Exposure
9 | Alamolhoda SH, Simbar M, Mirmiran P, et al. Effect of low trans-fatty acid intakes on preeclampsia: A randomized controlled trial. Journal of Research in Medical Sciences. 2020. 25. doi:10.4103/jrms.JRMS_149_19. | Intervention/Exposure; Outcome
10 | Allehdan S, Basha A, Hyassat D, et al. Effectiveness of carbohydrate counting and Dietary Approach to Stop Hypertension dietary intervention on managing Gestational Diabetes Mellitus among pregnant women who used metformin: A randomized controlled clinical trial. Clinical Nutrition. 2022. 41:384-395. doi:10.1016/j.clnu.2021.11.039. | Intervention/Exposure; Health Status
11 | Aminianfar A, Soltani S, Hajianfar H, et al. The association between dietary glycemic index and load and risk of gestational diabetes mellitus: A prospective study. Diabetes Research and Clinical Practice. 2020. 170. doi:10.1016/j.diabres.2020.108469. | Intervention/Exposure; Outcome
12 | Anand SS, Gupta M, Teo KK, et al. Causes and consequences of gestational diabetes in South Asians living in Canada: results from a prospective cohort study. CMAJ Open. 2017. 5:E604-e611. doi:10.9778/cmajo.20170027. | Outcome; Comparator
13 | Ancira-Moreno M, Vadillo-Ortega F, Rivera-Dommarco JÁ, et al. Gestational weight gain trajectories over pregnancy and their association with maternal diet quality: Results from the PRINCESA cohort. Nutrition. 2019. 65:158-166. doi:10.1016/j.nut.2019.02.002. | Outcome
14 | Anelli GM, Parisi F, Sarno L, et al. Associations between Maternal Dietary Patterns, Biomarkers and Delivery Outcomes in Healthy Singleton Pregnancies: Multicenter Italian GIFt Study. Nutrients. 2022 Sep 2. 14(17):3631. doi: 10.3390/nu14173631. | Outcome
15 | Angali KA, Shahri P, Borazjani F. Maternal dietary pattern in early pregnancy is associated with gestational weight gain and hyperglycemia: A cohort study in South West of Iran. Diabetes Metab Syndr. 2020. 14:1711-1717. doi:10.1016/j.dsx.2020.08.008. | Outcome
16 | Ansu V, He K. Previous preterm birth and the risk of recurrent preterm birth..Chia A-R, de Seymour JV, Colega M, et al. A vegetable, fruit, and white rice dietary pattern during pregnancy is associated with a lower risk of preterm birth and larger birth size in a multiethnic Asian cohort: the Growing Up in Singapore Towards healthy Outcomes (GUSTO) cohort study. Am J Clin Nutr Nov 2016. 104(5):1416–23. Am J Clin Nutr. 2017. 105:1010-1011. doi:10.3945/ajcn.116.149674. | Publication Status
17 | Araki S, Shani Levi C, Abutbul Vered S, et al. Pregnancy after bariatric surgery: Effects of personalized nutrition counseling on pregnancy outcomes. Clin Nutr. 2022. 41:288-297. doi:10.1016/j.clnu.2021.11.035. | Comparator
18 | Assaf-Balut C, de la Torre NG, Fuentes M, et al. A high adherence to six food targets of the mediterranean diet in the late first trimester is associated with a reduction in the risk of maternofoetal outcomes: The st. carlos gestational diabetes mellitus prevention study. Nutrients. 2019. 11. doi:10.3390/nu11010066. | Confounders
19 | Assaf-Balut C, Garcia de la Torre N, Bordiu E, et al. Consumption of fat-free dairy products is not associated with a lower risk of maternofetal adverse events. BMJ Open Diabetes Res Care. 2020. 8. doi:10.1136/bmjdrc-2019-001145. | Intervention/Exposure
20 | Assaf-Balut C, Garcia de la Torre N, Durán A, et al. Medical nutrition therapy for gestational diabetes mellitus based on Mediterranean Diet principles: a subanalysis of the St Carlos GDM Prevention Study. BMJ Open Diabetes Res Care. 2018. 6:e000550. doi:10.1136/bmjdrc-2018000550. | Intervention/Exposure; Comparator
21 | Atkinson SA, Maran A, Dempsey K, et al. Be Healthy in Pregnancy (BHIP): A Randomized Controlled Trial of Nutrition and Exercise Intervention from Early Pregnancy to Achieve Recommended Gestational Weight Gain. Nutrients. 2022. 14. doi:10.3390/nu14040810. | Intervention/Exposure
22 | Augustin H, Winkvist A, Bärebring L. Poor Dietary Quality is Associated with Low Adherence to Gestational Weight Gain Recommendations among Women in Sweden. Nutrients. 2020. 12. doi:10.3390/nu12020317. | Outcome
23 | Avnon T, Paz Dubinsky E, Lavie I, et al. The impact of a vegan diet on pregnancy outcomes. J Perinatol. 2021. 41:1129-1133. doi:10.1038/s41372-020-00804-x. | Intervention/Exposure
24 | Babili MG, Amerikanou C, Papada E, et al. The effect of prenatal maternal physical activity and lifestyle in perinatal outcome: results from a Greek study. Eur J Public Health. 2020. 30:328-332. doi:10.1093/eurpub/ckz223. | Study Design; Outcome
25 | Badon SE, Miller RS, Qiu C, et al. Maternal healthy lifestyle during early pregnancy and offspring birthweight: differences by offspring sex. J Matern Fetal Neonatal Med. 2018. 31:1111-1117. doi:10.1080/14767058.2017.1309383. | Outcome
26 | Barquiel B, Calvo M, Moreno-Dominguez O, et al. The PREDG study: A randomised controlled trial testing whether an educational intervention can prevent gestational weight gain in women with obesity. Clinical Nutrition ESPEN. 2023. 57:266. doi:10.1016/j.clnesp.2023.07.006. | Intervention/Exposure
27 | Bédard A, Northstone K, John Henderson A, et al. Mediterranean diet during pregnancy and childhood respiratory and atopic outcomes: Birth cohort study. European Respiratory Journal. 2020. 55. doi:10.1183/13993003.01215-2019. | Life Stage; Confounders
28 | Belfort GP, De Padilha PC, Farias DR, et al. Effect of the Dietary Approaches to Stop Hypertension (DASH) diet on the development of preeclampsia and metabolic outcomes in pregnant women with pre-existing diabetes mellitus: A randomised, controlled, single-blind trial. Journal of Nutritional Science. 2023. 12. doi:10.1017/jns.2023.54. | Health Status
29 | Bodnar LM, Cartus AR, Kennedy EH, et al. Use of a Doubly Robust Machine-Learning-Based Approach to Evaluate Body Mass Index as a Modifier of the Association Between Fruit and Vegetable Intake and Preeclampsia. Am J Epidemiol. 2022 Jul 23. 191(8):1396-1406. doi: 10.1093/aje/kwac062. | Intervention/Exposure; Outcome
30 | Bonakdar SA, Dorosty Motlagh AR, Bagherniya M, et al. Pre-pregnancy Body Mass Index and Maternal Nutrition in Relation to Infant Birth Size. Clin Nutr Res. 2019. 8:129-137. doi:10.7762/cnr.2019.8.2.129. | Study Design; Intervention/Exposure
31 | Brei C, Stecher L, Meyer DM, et al. Impact of Dietary Macronutrient Intake during Early and Late Gestation on Offspring Body Composition at Birth, 1, 3, and 5 Years of Age. Nutrients. 2018. 10. doi:10.3390/nu10050579. | Intervention/Exposure
32 | Bruno R, Petrella E, Bertarini V, et al. Adherence to a lifestyle programme in overweight/obese pregnant women and effect on gestational diabetes mellitus: a randomized controlled trial. Matern Child Nutr. 2017. 13. doi:10.1111/mcn.12333. | Intervention/Exposure
33 | Brzozowska A, Podlecka D, Jankowska A, et al. Maternal diet during pregnancy and risk of allergic diseases in children up to 7–9 years old from Polish Mother and Child Cohort study. Environmental Research. 2022. 208. doi:10.1016/j.envres.2022.112682. | Outcome
34 | Buckingham-Schutt LM, Ellingson LD, Vazou S, et al. The Behavioral Wellness in Pregnancy study: a randomized controlled trial of a multi-component intervention to promote appropriate weight gain. Am J Clin Nutr. 2019. 109:1071-1079. doi:10.1093/ajcn/nqy359. | Intervention/Exposure; Comparator
35 | Buxton MA, Perng W, Tellez-Rojo MM, et al. Particulate matter exposure, dietary inflammatory index and preterm birth in Mexico city, Mexico. Environ Res. 2020. 189:109852. doi:10.1016/j.envres.2020.109852. | Intervention/Exposure
36 | Call CC, Magee K, Conlon RPK, et al. Disordered eating during pregnancy among individuals participating in the Special Supplemental Nutrition Program for Women, Infants, and Children (WIC). Eating Behaviors. 2023. 49. doi:10.1016/j.eatbeh.2023.101726. | Intervention/Exposure; Outcome
37 | Calvo-Lerma J, Selma-Royo M, Hervas D, et al. Breast Milk Lipidome Is Associated With Maternal Diet and Infants’ Growth. Front Nutr. 2022 Jul 6. 9:854786. doi: 10.3389/fnut.2022.854786. eCollection 2022. | Intervention/Exposure; Outcome
38 | Cano-Ibáñez N, Martínez-Galiano JM, Luque-Fernández MA, et al. Maternal dietary patterns during pregnancy and their association with gestational weight gain and nutrient adequacy. International Journal of Environmental Research and Public Health. 2020. 17:1-13. doi:10.3390/ijerph17217908. | Study Design; Outcome
39 | Carolan-Olah M, Sayakhot P. A randomized controlled trial of a web-based education intervention for women with gestational diabetes mellitus. Midwifery. 2019. 68:39-47. doi:10.1016/j.midw.2018.08.019. | Intervention/Exposure
40 | Casas R, Castro-Barquero S, Crovetto F, et al. Maternal Dietary Inflammatory Index during Pregnancy Is Associated with Perinatal Outcomes: Results from the IMPACT BCN Trial. Nutrients. 2022. 14. doi:10.3390/nu14112284. | Intervention/Exposure
41 | Charkamyani F, Khedmat L, Hosseinkhani A. Decreasing the main maternal and fetal complications in women undergoing in vitro fertilization (IVF) trained by nutrition and healthy eating practices during pregnancy. J Matern Fetal Neonatal Med. 2021. 34:1855-1867. doi:10.1080/14767058.2019.1651267. | Life Stage
42 | Chen LW, Aubert AM, Shivappa N, et al. Maternal dietary quality, inflammatory potential and childhood adiposity: an individual participant data pooled analysis of seven European cohorts in the ALPHABET consortium. BMC Med. 2021. 19:33. doi:10.1186/s12916-021-01908-7. | Outcome
43 | Chen LW, Fitzgerald R, Murrin CM, et al. Associations of maternal caffeine intake with birth outcomes: results from the Lifeways Cross Generation Cohort Study. Am J Clin Nutr. 2018. 108:1301-1308. doi:10.1093/ajcn/nqy219. | Intervention/Exposure
44 | Chen Y, Qin Y, Zhang Z, et al. Association of the low-carbohydrate dietary pattern with postpartum weight retention in women. Food Funct. 2021. 12:10764-10772. doi:10.1039/d1fo00935d. | Study Design
45 | Chia AR, de Seymour JV, Wong G, et al. Maternal plasma metabolic markers of neonatal adiposity and associated maternal characteristics: The GUSTO study. Sci Rep. 2020. 10:9422. doi:10.1038/s41598-020-66026-5. | Comparator
46 | Coathup V, Northstone K, Gray R, et al. Dietary Patterns and Alcohol Consumption During Pregnancy: Secondary Analysis of Avon Longitudinal Study of Parents and Children. Alcoholism: Clinical and Experimental Research. 2017. 41:1120-1128. doi:10.1111/acer.13379. | Outcome
47 | Cohen CC, Perng W, Sauder KA, et al. Maternal Diet Quality During Pregnancy and Offspring Hepatic Fat in Early Childhood: The Healthy Start Study. Journal of Nutrition. 2023. 153:1122. doi:10.1016/j.tjnut.2023.01.039. | Outcome
48 | Comas Rovira M, Moreno Baró A, Burgaya Guiu N, et al. The influence of obesity and diet quality on fetal growth and perinatal outcome. Nutr Hosp. 2022 Sep 21. doi: 10.20960/nh.04076. | Confounders
49 | Conradie C, Baumgartner J, Malan L, et al. A Priori and a Posteriori Dietary Patterns among Pregnant Women in Johannesburg, South Africa: The NuPED Study. Nutrients. 2021. 13. doi:10.3390/nu13020565. | Outcome; Comparator
50 | Corsi Decenti E, Zambri F, Salvatore MA, et al. Dietary habits, lifestyle, and gestational diabetes in immigrant women: a survey in Northwestern Tuscany (Central Italy). Epidemiol Prev. 2022 Jul-Aug. 46(4):259-267. doi: 10.19191/EP22.4.A372.074. | Intervention/Exposure; Comparator
51 | Costanza J, Camanni M, Ferrari MM, et al. Assessment of pregnancy dietary intake and association with maternal and neonatal outcomes. Pediatr Res. 2021. doi:10.1038/s41390-02101665-6. | Study Design; Intervention/Exposure
52 | Crovetto F, Nakaki A, Arranz A, et al. Effect of a Mediterranean Diet or Mindfulness-Based Stress Reduction During Pregnancy on Child Neurodevelopment: A Prespecified Analysis of the IMPACT BCN Randomized Clinical Trial. JAMA Netw Open. 2023 Aug 1. 6(8):e2330255. doi: 10.1001/jamanetworkopen.2023.30255. | Outcome; Data Overlap
53 | Crovetto F, Crispi F, Gratacós E. Mediterranean Diet or Mindfulness-Based Stress Reduction and Prevention of Small-for-Gestational-Age Birth Weights in Newborns-Reply. JAMA: Journal of the American Medical Association. 2022. 327:1293-1294. doi:10.1001/jama.2022.2167. | Publication Status
54 | Cui N, Li Y, Huang S, et al. Cholesterol-rich dietary pattern during early pregnancy and genetic variations of cholesterol metabolism genes in predicting gestational diabetes mellitus: a nested case-control study. American Journal of Clinical Nutrition. 2023. 118:966. doi:10.1016/j.ajcnut.2023.08.017. | Outcome
55 | Cummings JR, Faith MS, Lipsky LM, Liu A, Mooney JT, Nansel TR. Prospective relations of maternal reward-related eating, pregnancy ultra-processed food intake and weight indicators, and feeding mode with infant appetitive traits. Int J Behav Nutr Phys Act. 2022 Aug 3. 19(1):100. doi: 10.1186/s12966-022-01334-9. | Intervention/Exposure; Outcome
56 | da Mota Santana J, de Oliveira Queiroz VA, Pereira M, et al. Associations between Maternal Dietary Patterns and Infant Birth Weight in the NISAMI Cohort: A Structural Equation Modeling Analysis. Nutrients. 2021. 13. doi:10.3390/nu13114054. | Outcome
57 | Dalfrà MG, Del Vescovo GG, Burlina S, et al. Celiac Disease and Pregnancy Outcomes in Patients with Gestational Diabetes Mellitus. Int J Endocrinol. 2020. 2020:5295290. doi:10.1155/2020/5295290. | Intervention/Exposure
58 | Dalrymple KV, Vogel C, Godfrey KM, et al. Longitudinal dietary trajectories from preconception to mid-childhood in women and children in the Southampton Women’s Survey and their relation to offspring adiposity: a group-based trajectory modelling approach. International Journal of Obesity. 2022. 46:758-766. doi:10.1038/s41366-021-01047-2. | Life Stage
59 | Damen NA, Gillingham M, Hansen JG, et al. Maternal dietary fat intake during pregnancy and newborn body composition. Journal of Perinatology. 2021. 41:1007-1013. doi:10.1038/s41372021-00922-0. | Intervention/Exposure
60 | Dancause KN, Mutran D, Elgbeili G, et al. Dietary change mediates relationships between stress during pregnancy and infant head circumference measures: the QF2011 study. Maternal and Child Nutrition. 2017. 13. doi:10.1111/mcn.12359. | Outcome
61 | de Almeida VAH, da Costa RA, Paganoti CF, et al. Diet quality indices and physical activity levels associated with adequacy of gestational weight gain in pregnant women with gestational diabetes mellitus. Nutrients. 2021. 13. doi:10.3390/nu13061842. | Outcome
62 | De Giuseppe R, Bocchi M, Maffoni S, et al. Mediterranean Diet and Lifestyle Habits during Pregnancy: Is There an Association with Small for Gestational Age Infants? An Italian Single Centre Experience. Nutrients. 2021. 13. doi:10.3390/nu13061941. | Study Design
63 | de Jersey S, Meloncelli N, Guthrie T, et al. Outcomes from a hybrid implementation-effectiveness study of the living well during pregnancy Tele-coaching program for women at high risk of excessive gestational weight gain. BMC Health Serv Res. 2022. 22:589. doi:10.1186/s12913-02208002-5. | Outcome
64 | de la Torre NG, Assaf-Balut C, Jiménez Varas I, et al. Effectiveness of Following Mediterranean Diet Recommendations in the Real World in the Incidence of Gestational Diabetes Mellitus (GDM) and Adverse Maternal-Foetal Outcomes: A Prospective, Universal, Interventional Study with a Single Group. The St Carlos Study. Nutrients. 2019. 11. doi:10.3390/nu11061210. | Intervention/Exposure; Comparator
65 | de Lima MC, Santos IDS, Crivellenti LC, et al. A better quality of maternal dietary fat reduces the chance of large-for-gestational-age infants: A prospective cohort study. Nutrition. 2021. 9192:111367. doi:10.1016/j.nut.2021.111367. | Intervention/Exposure
66 | Dhana K, Haines J, Liu G, et al. Association between maternal adherence to healthy lifestyle practices and risk of obesity in offspring: results from two prospective cohort studies of motherchild pairs in the United States. Bmj. 2018. 362:k2486. doi:10.1136/bmj.k2486. | Life Stage
67 | Dodd JM, Deussen AR, Peña AS, Mitchell M, Louise J. Effects of an antenatal dietary intervention in women with obesity or overweight on child outcomes at 8-10 years of age: LIMIT randomised trial follow-up. BMC Pediatr. 2023 Dec 19. 23(1):643. doi: 10.1186/s12887-023-04466-4. | Outcome; Life Stage
68 | Dorise B, Byth K, McGee T, et al. A low intensity dietary intervention for reducing excessive gestational weight gain in an overweight and obese pregnant cohort. Eat Weight Disord. 2020. 25:257-263. doi:10.1007/s40519-018-0566-2. | Intervention/Exposure
69 | Duran A. Meddiet at early gestation reduces gestational diabetes mellitus (GDM) incidence and adverse gestational and neonatal outcomes. Diabetes. 2017. 66:A387-. | Publication Status
70 | El-Gamasy BSM, Hassan SA, Ghonemy GE, et al. Effect of Lifestyle Modification on Pregnancy Outcomes among Women with Gestational Diabetes: Quasi Randomized Controlled Trail (QRCT). NeuroQuantology. 2022. 20:6068. doi:10.14704/nq.2022.20.6.NQ22611. | Intervention/Exposure
71 | Elvebakk T, Mostad IL, Mørkved S, et al. Dietary Intakes and Dietary Quality during Pregnancy in Women with and without Gestational Diabetes Mellitus-A Norwegian Longitudinal Study. Nutrients. 2018. 10. doi:10.3390/nu10111811. | Intervention/Exposure; Outcome
72 | Englund-Ögge L, Birgisdottir BE, Sengpiel V, et al. Meal frequency patterns and glycemic properties of maternal diet in relation to preterm delivery: Results from a large prospective cohort study. PLoS ONE. 2017. 12. doi:10.1371/journal.pone.0172896. | Intervention/Exposure
73 | Kennedy ET. A prenatal screening system for use in a community-based setting. Journal of the American Dietetic Association. 1986. 86:1372-5. | Confounders
74 | Facchinetti F, Vijai V, Petrella E, et al. Food glycemic index changes in overweight/obese pregnant women enrolled in a lifestyle program: a randomized controlled trial. Am J Obstet Gynecol MFM. 2019. 1:100030. doi:10.1016/j.ajogmf.2019.100030. | Intervention/Exposure; Comparator
75 | Facchinetti F, Vijay V, Petrella E, et al. 78: impact of glycemic-index(GI) reduction on birthweight in overweight/obese pregnant women enrolled in a lifestyle program. American journal of obstetrics and gynecology. 2019. 220:S62-. doi:10.1016/j.ajog.2018.11.086. | Study Design; Publication Status
76 | Fahey CA, Chevrier J, Crause M, et al. Seasonality of antenatal care attendance, maternal dietary intake, and fetal growth in the VHEMBE birth cohort, South Africa. PLoS One. 2019. 14:e0222888. doi:10.1371/journal.pone.0222888. | Intervention/Exposure
77 | Ferrara P, Sandullo F, Di Ruscio F, et al. The impact of lacto-ovo-/lacto-vegetarian and vegan diets during pregnancy on the birth anthropometric parameters of the newborn. J Matern Fetal Neonatal Med. 2019. 1-7. doi:10.1080/14767058.2019.1590330. | Intervention/Exposure
78 | Ferrara P, Sandullo F, Vecchio M, et al. Length-weight growth analysis up to 12 months of age in three groups according to the dietary pattern followed from pregnant mothers and children during the first year of life. Minerva Pediatr (Torino). 2021. doi:10.23736/s2724-5276.21.06262-5. | Intervention/Exposure
79 | Ferreira LB, Lobo CV, do Carmo AS, et al. Dietary Patterns During Pregnancy and Their Association with Gestational Weight Gain and Anthropometric Measurements at Birth. Matern Child Health J. 2022. 26:1464-1472. doi:10.1007/s10995-022-03392-8. | Study Design
80 | Francis EC, Dabelea D, Boyle KE, et al. Maternal Diet Quality Is Associated with Placental Proteins in the Placental Insulin/Growth Factor, Environmental Stress, Inflammation, and mTOR Signaling Pathways: The Healthy Start ECHO Cohort. J Nutr. 2022. 152:816-825. doi:10.1093/jn/nxab403. | Outcome
81 | Garay SM, Sumption LA, John RM. Prenatal health behaviours as predictors of human placental lactogen levels. Frontiers in Endocrinology. 2022. 13. doi:10.3389/fendo.2022.946539. | Study Design
82 | Geiker NRW, Magkos F, Zingenberg H, et al. A high-protein low-glycemic index diet attenuates gestational weight gain in pregnant women with obesity: The “An optimized programming of healthy children” (APPROACH) randomized controlled trial. American Journal of Clinical Nutrition. 2022. 115:970-979. doi:10.1093/ajcn/nqab405. | Intervention/Exposure; Outcome
83 | Geraghty AA, Sexton-Oates A, O’Brien EC, et al. A Low Glycaemic Index Diet in Pregnancy Induces DNA Methylation Variation in Blood of Newborns: Results from the ROLO Randomised Controlled Trial. Nutrients. 2018. 10. doi:10.3390/nu10040455. | Intervention/Exposure
84 | Gershuni V, Li Y, Elovitz M, et al. Maternal gut microbiota reflecting poor diet quality is associated with spontaneous preterm birth in a prospective cohort study. Am J Clin Nutr. 2021. 113:602-611. doi:10.1093/ajcn/nqaa361. | Intervention/Exposure
85 | Gete DG, Waller M, Mishra GD. Pre-pregnancy diet quality is associated with lowering the risk of offspring obesity and underweight: Finding from a prospective cohort study. Nutrients. 2021. 13. doi:10.3390/nu13041044. | Outcome; Comparator
86 | Gete DG, Waller M, Mishra GD. Prepregnancy dietary patterns and risk of preterm birth and low birth weight: findings from the Australian Longitudinal Study on Women’s Health. Am J Clin Nutr. 2020. 111:1048-1058. doi:10.1093/ajcn/nqaa057. | Life Stage
87 | Ghorbani-Kafteroodi S, Ghiasvand M, Saghafi-Asl M, Kazemi Aski S. Association of dietary patterns of pregnant women with pregnancy outcomes: A hospital-based study. Food Sci Nutr. 2023 Oct 3. 11(12):8072-8081. doi: 10.1002/fsn3.3726. eCollection 2023 Dec. | Study Design; Outcome
88 | Gómez Roig MD, Mazarico E, Ferrero S, et al. Differences in dietary and lifestyle habits between pregnant women with small fetuses and appropriate-for-gestational-age fetuses. J Obstet Gynaecol Res. 2017. 43:1145-1151. doi:10.1111/jog.13330. | Study Design
89 | Gontijo CA, Balieiro LCT, Teixeira GP, et al. Effects of timing of food intake on eating patterns, diet quality and weight gain during pregnancy. Br J Nutr. 2020. 123:922-933. doi:10.1017/s0007114519003398. | Intervention/Exposure; Outcome
90 | Gonzalez-Nahm S, Marchesoni J, Maity A, et al. Maternal Mediterranean Diet Adherence and Its Associations with Maternal Prenatal Stressors and Child Growth. Curr Dev Nutr. 2022 Nov 15. 6(11):nzac146. doi: 10.1093/cdn/nzac146. eCollection 2022 Nov. | Outcome
91 | Gonzalez-Nahm S, Mendez M, Robinson W, et al. Low maternal adherence to a Mediterranean diet is associated with increase in methylation at the MEG3-IG differentially methylated region in female infants. Environ Epigenet. 2017. 3:dvx007. doi:10.1093/eep/dvx007. | Confounders
92 | Gonzalez-Nahm S, Nihlani K, House JS, et al. Associations between Maternal Cadmium Exposure with Risk of Preterm Birth and Low after Birth Weight Effect of Mediterranean Diet Adherence on Affected Prenatal Outcomes. Toxics. 2020. 8. doi:10.3390/toxics8040090. | Intervention/Exposure; Comparator
93 | Grandy M, Snowden JM, Boone-Heinonen J, et al. Poorer maternal diet quality and increased birth weight(). J Matern Fetal Neonatal Med. 2018. 31:1613-1619. doi:10.1080/14767058.2017.1322949. | Outcome
94 | Greathouse KL, Padgett RN, Petrosino J, et al. Exploration of Diet Quality by Obesity Severity in Association with Gestational Weight Gain and Distal Gut Microbiota in Pregnant African American Women: Opportunities for Intervention. Matern Child Health J. 2022. 26:882-894. doi:10.1007/s10995-021-03198-0. | Outcome
95 | Günther J, Hoffmann J, Spies M, et al. Associations between the Prenatal Diet and Neonatal Outcomes-A Secondary Analysis of the Cluster-Randomised GeliS Trial. Nutrients. 2019. 11. doi:10.3390/nu11081889. | Intervention/Exposure
96 | Hamad R, Collin DF, Baer RJ, et al. Association of Revised WIC Food Package With Perinatal and Birth Outcomes: A Quasi-Experimental Study. JAMA Pediatrics. 2019. 173:845-852. doi:10.1001/jamapediatrics.2019.1706. | Intervention/Exposure
97 | Haruna M, Shiraishi M, Matsuzaki M, et al. Effect of tailored dietary guidance for pregnant women on nutritional status: A double-cohort study. Matern Child Nutr. 2017. 13. doi:10.1111/mcn.12391. | Intervention/Exposure
98 | Harvey M, Zagarins S, Marcus B, et al. The association between diet quality indices and gestational age and birth weight among Latinas. Paediatric and perinatal epidemiology. 2021. 35:56. doi:10.1111/ppe.12814. | Publication Status
99 | Harville EW, Lewis CE, Catov JM, et al. A longitudinal study of pre-pregnancy antioxidant levels and subsequent perinatal outcomes in black and white women: The CARDIA Study. PLoS One. 2020. 15:e0229002. doi:10.1371/journal.pone.0229002. | Intervention/Exposure
100 | Hasken JM, de Vries MM, Marais AS, et al. Maternal dietary intake among alcohol-exposed pregnancies is linked to early infant physical outcomes in South Africa. Reprod Toxicol. 2023 Sep 9. 121:108467. doi: 10.1016/j.reprotox.2023.108467. | Intervention/Exposure
101 | Heslehurst N, Flynn AC, Ngongalah L, et al. Diet, Physical Activity and Gestational Weight Gain Patterns among Pregnant Women Living with Obesity in the North East of England: The GLOWING Pilot Trial. Nutrients. 2021. 13. doi:10.3390/nu13061981. | Intervention/Exposure; Outcome
102 | Hezaveh ZS, Feizy Z, Dehghani F, et al. The association between maternal dietary protein intake and risk of gestational diabetes mellitus. International Journal of Preventive Medicine. 2019. 10. doi:10.4103/ijpvm.IJPVM_86_19. | Study Design
103 | Hirko KA, Comstock SS, Strakovsky RS, et al. Diet during Pregnancy and Gestational Weight Gain in a Michigan Pregnancy Cohort. Curr Dev Nutr. 2020. 4:nzaa121. doi:10.1093/cdn/nzaa121. | Intervention/Exposure; Outcome
104 | Hoffmann J, Gunther J, Stecher L, et al. Does an antenatal lifestyle intervention in routine care improve maternal and infant health outcomes in the first year postpartum-12 months follow-up of the cluster-randomised GeliS trial. Obesity reviews. 2020. 21. doi:10.1111/obr.13118. | Publication Status
105 | Hoirisch-Clapauch S, Constan Werneck Sant’Anna M, Cinelli Couto Moreira E, et al. Lifestyle modification increases the take-home baby rate in women with recurrent early miscarriages: a randomised study. Thrombosis Research. 2017. 151:S104-. | Publication Status; Publication Date
106 | Hu J, Gao M, Ma Y, et al. The Association between Dietary Patterns and Pre-Pregnancy BMI with Gestational Weight Gain: The “Born in Shenyang” Cohort. Nutrients. 2022 Jun 20. 14(12):2551. doi: 10.3390/nu14122551. | Outcome
107 | Hu J, Aris IM, Lin PD, et al. Association of Maternal Dietary Patterns during Pregnancy and Offspring Weight Status across Infancy: Results from a Prospective Birth Cohort in China. Nutrients. 2021. 13. doi:10.3390/nu13062040. | Outcome
108 | Hu J, Li L, Wan N, et al. Associations of Dietary Patterns during Pregnancy with Gestational Hypertension: The “Born in Shenyang” Cohort Study. Nutrients. 2022. 14. doi:10.3390/nu14204342. | Outcome
109 | Hu Z, Tylavsky FA, Kocak M, et al. Effects of maternal dietary patterns during pregnancy on early childhood growth trajectories and obesity risk: The CANDLE study. Nutrients. 2020. 12. doi:10.3390/nu12020465. | Confounders
110 | Huang L, Shang L, Yang W, et al. High starchy food intake may increase the risk of adverse pregnancy outcomes: a nested case-control study in the Shaanxi province of Northwestern China. BMC Pregnancy Childbirth. 2019. 19:362. doi:10.1186/s12884-019-2524-z. | Outcome
111 | Huang RC, Silva D, Beilin L, et al. Feasibility of conducting an early pregnancy diet and lifestyle ehealth intervention: the Pregnancy Lifestyle Activity Nutrition (PLAN) project. J Dev Orig Health Dis. 2020. 11:58-70. doi:10.1017/s2040174419000400. | Intervention/Exposure
112 | Huvinen E, Koivusalo SB, Meinilä J, et al. Effects of a Lifestyle Intervention during Pregnancy and First Postpartum Year: Findings from the RADIEL Study. Journal of Clinical Endocrinology and Metabolism. 2018. 103:1669-1677. doi:10.1210/jc.2017-02477. | Outcome
113 | Huynh DTT, Tran NT, Nguyen LT, et al. Maternal nutritional adequacy and gestational weight gain in vietnamese pregnant women. Annals of nutrition & metabolism. 2017. 71:629-. doi:10.1159/000480486. | Publication Status
114 | Hyde NK, Brennan-Olsen SL, Wark JD, et al. Maternal Dietary Nutrient Intake During Pregnancy and Offspring Linear Growth and Bone: The Vitamin D in Pregnancy Cohort Study. Calcified Tissue International. 2017. 100:47-54. doi:10.1007/s00223-016-0199-2. | Intervention/Exposure; Outcome
115 | Imai C, Takimoto H, Kurotani K, et al. Diet Quality and Its Relationship with Weight Characteristics in Pregnant Japanese Women: A Single-Center Birth Cohort Study. Nutrients. 2023 Apr 10. 15(8):1827. doi: 10.3390/nu15081827. | Intervention/Exposure; Outcome
116 | Ishitsuka K, Yamamoto-Hanada K, Mezawa H, et al. Association between pre-pregnancy weight status and dietary patterns during pregnancy: results from the Japan Environment and Children’s Study. Public Health Nutr. 2023 May 2:1-20. doi: 10.1017/S1368980023000770. | Outcome
117 | Itani L, Radwan H, Hashim M, et al. Dietary patterns and their associations with gestational weight gain in the United Arab Emirates: results from the MISC cohort. Nutr J. 2020. 19:36. doi:10.1186/s12937-020-00553-9. | Outcome
118 | Ito M, Takamori A, Yoneda S, et al. Fermented foods and preterm birth risk from a prospective large cohort study: the Japan Environment and Children’s study. Environ Health Prev Med. 2019. 24:25. doi:10.1186/s12199-019-0782-z. | Intervention/Exposure
119 | James-McAlpine JM, Vincze LJ, Vanderlelie JJ, et al. Influence of dietary intake and decisionmaking during pregnancy on birth outcomes. Nutr Diet. 2020. 77:323-330. doi:10.1111/17470080.12610. | Intervention/Exposure
120 | Jayedi A, Zeraattalab-Motlagh S, Moosavi H, et al. Association of plant-based dietary patterns in first trimester of pregnancy with gestational weight gain: results from a prospective birth cohort. Eur J Clin Nutr. 2023 Feb 14. doi: 10.1038/s41430-023-01275-x. | Outcome
121 | Jiang F, Li Y, Xu P, et al. The efficacy of the Dietary Approaches to Stop Hypertension diet with respect to improving pregnancy outcomes in women with hypertensive disorders. J Hum Nutr Diet. 2019. 32:713-718. doi:10.1111/jhn.12654. | Intervention/Exposure; Comparator
122 | Kaneko K, Ito Y, Ebara T, et al. High Maternal Total Cholesterol Is Associated With No-Catch-up Growth in Full-Term SGA Infants: The Japan Environment and Children’s Study. Frontiers in Endocrinology. 2022. 13. doi:10.3389/fendo.2022.939366. | Intervention/Exposure; Health Status
123 | Karimi T, Eini-Zinab H, Rezazadeh A, et al. Maternal dietary diversity and nutritional adequacy in relation with anthropometric measurements of newborns at birth: a cohort study in Tehran city. BMC Pediatr. 2022. 22:129. doi:10.1186/s12887-021-03102-3. | Outcome
124 | Kennedy RAK, Mullaney L, O’Higgins AC, et al. The relationship between early pregnancy dietary intakes and subsequent birthweight and neonatal adiposity. J Public Health (Oxf). 2018. 40:747755. doi:10.1093/pubmed/fdx131. | Intervention/Exposure
125 | Kennedy RAK, Reynolds CME, Cawley S, et al. web-based dietary intervention in early pregnancy and neonatal outcomes: a randomized controlled trial. Journal of Public Health. 2019. 41:371-378. doi:10.1093/pubmed/fdy117. | Intervention/Exposure
126 | Kennedy RAK, Reynolds CME, O’Malley EG, et al. Assessing maternal dietary quality in early pregnancy in the programming of intrauterine fetal growth. Acta Obstet Gynecol Scand. 2020. 99:510-517. doi:10.1111/aogs.13768. | Intervention/Exposure
127 | Kennedy RAK, Turner MJ. Development of a novel Periconceptual Nutrition Score (PENS) to examine the relationship between maternal dietary quality and fetal growth. Early Hum Dev. 2019. 132:6-12. doi:10.1016/j.earlhumdev.2019.03.004. | Intervention/Exposure
128 | Kesary Y, Avital K, Hiersch L. Maternal plant-based diet during gestation and pregnancy outcomes. Arch Gynecol Obstet. 2020. 302:887-898. doi:10.1007/s00404-020-05689-x. | Study Design
129 | Kim MJ, Lim HS, Lee HH, et al. Dietary assessment, nutrition knowledge, and pregnancy outcome in high-risk pregnant Korean women. Clinical and Experimental Obstetrics and Gynecology. 2021. 48:1178-1185. doi:10.31083/j.ceog4805188. | Intervention/Exposure; Comparator
130 | Krzeczkowski JE, Boylan K, Arbuckle TE, et al. Maternal pregnancy diet quality is directly associated with autonomic nervous system function in 6-month-old offspring. Journal of Nutrition. 2020. 150:267-275. doi:10.1093/jn/nxz228. | Outcome
131 | Kunath J, Günther J, Rauh K, et al. Effects of a lifestyle intervention during pregnancy to prevent excessive gestational weight gain in routine care - the cluster-randomised GeliS trial. BMC Med. 2019. 17:5. doi:10.1186/s12916-018-1235-z. | Intervention/Exposure
132 | Kyrkou C, Fotakis C, Dimitropoulou A, et al. Maternal Dietary Protein Patterns and Neonatal Anthropometrics: A Prospective Study with Insights from NMR Metabolomics in Amniotic Fluid. Metabolites. 2023 Aug 29. 13(9):977. doi: 10.3390/metabo13090977. | Outcome; Confounders
133 | Lai JS, Soh SE, Colega M, et al. Macronutrient composition and food groups associated with gestational weight gain: the GUSTO study. European Journal of Nutrition. 2019. 58:1081-1094. doi:10.1007/s00394-018-1623-3. | Outcome
134 | Laursen ASD, Johannesen BR, Willis SK, et al. Adherence to Nordic dietary patterns and risk of first-trimester spontaneous abortion. European Journal of Nutrition. 2022. 61:3255. doi:10.1007/s00394-022-02886-z. | Outcome
135 | Lavie M, Lavie I, Maslovitz S. Paleolithic diet during pregnancy-A potential beneficial effect on metabolic indices and birth weight. Eur J Obstet Gynecol Reprod Biol. 2019. 242:7-11. doi:10.1016/j.ejogrb.2019.08.013. | Study Design
136 | Lecorguillé M, Schipper M, O’Donnell A, et al. Parental lifestyle patterns around pregnancy and risk of childhood obesity in four European birth cohort studies. Lancet Glob Health. 2023 Mar. 11 Suppl 1:S5. doi: 10.1016/S2214-109X(23)00090-6. | Publication Status
137 | Lecorguille M, Mcauliffe FM, Twomey PJ, et al. Maternal Glycaemic and Insulinemic Status and Newborn DNA Methylation: Findings in Women With Overweight and Obesity. Journal of Clinical Endocrinology and Metabolism. 2023. 108:85. doi:10.1210/clinem/dgac553. | Intervention/Exposure; Outcome
138 | Lee E, Kim H, Kim H, et al. Association of maternal omega-6 fatty acid intake with infant birth outcomes: Korean Mothers and Children’s Environmental Health (MOCEH). Nutr J. 2018. 17:47. doi:10.1186/s12937-018-0353-y. | Intervention/Exposure
139 | Lee YQ, Lumbers ER, Schumacher TL, et al. Maternal Diet Influences Fetal Growth but Not Fetal Kidney Volume in an Australian Indigenous Pregnancy Cohort. Nutrients. 2021. 13. doi:10.3390/nu13020569. | Outcome
140 | Li LJ, Aris IM, Han WM, et al. A Promising Food-Coaching Intervention Program to Achieve Optimal Gestational Weight Gain in Overweight and Obese Pregnant Women: Pilot Randomized Controlled Trial of a Smartphone App. JMIR Form Res. 2019. 3:e13013. doi:10.2196/13013. | Intervention/Exposure
141 | Li N, Su X, Liu T, et al. Dietary patterns of Chinese puerperal women and their association with postpartum weight retention: Results from the mother-infant cohort study. Matern Child Nutr. 2021. 17:e13061. doi:10.1111/mcn.13061. | Study Design; Outcome
142 | Li S, Liu D, Kang Y, et al. Associations of B Vitamin-Related Dietary Pattern during Pregnancy with Birth Outcomes: A Population-Based Study in Northwest China. Nutrients. 2022. 14. doi:10.3390/nu14030600. | Study Design
143 | Ling-Wei C, Pei-Chi Shek L, Yung Seng L, et al. Associations of Maternal Dietary Patterns during Pregnancy with Offspring Adiposity from Birth Until 54 Months of Age. Nutrients. 2017. 9:2. doi:10.3390/nu9010002. | Outcome
144 | Lipsky LM, Burger K, Cummings JR, Faith MS, Nansel TR. Associations of parent feeding behaviors and early life food exposures with early childhood appetitive traits in an observational cohort study. Physiol Behav. 2023 Mar 28:114175. doi: 10.1016/j.physbeh.2023.114175. | Intervention/Exposure; Outcome; Life Stage
145 | Liu S-T, Lin C-C, Wei JC-C. Mediterranean Diet or Mindfulness-Based Stress Reduction and Prevention of Small-for-Gestational-Age Birth Weights in Newborns. JAMA: Journal of the American Medical Association. 2022. 327:1292-1293. doi:10.1001/jama.2022.2164. | Publication Status
146 | Liu Y-H, Lu L-P, Yi M-H, et al. Study on the correlation between homocysteine-related dietary patterns and gestational diabetes mellitus:a reduced-rank regression analysis study. BMC Pregnancy and Childbirth. 2022. 22. doi:10.1186/s12884-022-04656-5. | Outcome
147 | Liu Y-H, Zheng L, Cheng C, et al. Dietary inflammatory index, inflammation biomarkers and preeclampsia risk: A hospital-based case-control study. British Journal of Nutrition. 2023. 129:1528. doi:10.1017/S0007114522001489. | Study Design; Intervention/Exposure
148 | Louise J, Poprzeczny AJ, Deussen AR, et al. The effects of dietary and lifestyle interventions among pregnant women with overweight or obesity on early childhood outcomes: an individual participant data meta-analysis from randomised trials. BMC Medicine. 2021. 19:1-15. doi:10.1186/s12916-021-01995-6. | Comparator
149 | Ma L, Lu Q, Ouyang J, et al. How are maternal dietary patterns and maternal/fetal cytokines associated with birth weight? A path analysis. Br J Nutr. 2019. 121:1178-1187. doi:10.1017/s0007114519000382. | Outcome
150 | Mackeen AD, Young AJ, Lutcher S, et al. Encouraging appropriate gestational weight gain in highrisk gravida: A randomized controlled trial. Obesity Science and Practice. 2022. 8:261. doi:10.1002/osp4.565. | Intervention/Exposure
151 | Marchioro L, Hellmuth C, Uhl O, et al. Associations of maternal and fetal SCD-1 markers with infant anthropometry and maternal diet: Findings from the ROLO study. Clinical Nutrition. 2020. 39:21292136. doi:10.1016/j.clnu.2019.08.030. | Intervention/Exposure; Outcome
152 | Maslin K, Venter C, Palumbo M, et al. Temporal change in maternal dietary intake during pregnancy and lactation between and within 2 pregnancy cohorts assembled in the United Kingdom. Journal of Allergy and Clinical Immunology: In Practice. 2020. 8:1088-1090.e5. doi:10.1016/j.jaip.2019.11.041. | Publication Status
153 | Maugeri A, Barchitta M, Favara G, et al. Maternal dietary patterns are associated with prepregnancy body mass index and gestational weight gain: Results from the “mamma & bambino” cohort. Nutrients. 2019. 11. doi:10.3390/nu11061308. | Outcome; Confounders
154 | Mazurkiewicz D, Bronkowska M. Circulating Insulin and IGF-1 and Frequency of Food Consumption during Pregnancy as Predictors of Birth Weight and Length. Nutrients. 2021. 13:2344-2344. doi:10.3390/nu13072344. | Intervention/Exposure
155 | McCullough LE, Miller EE, Calderwood LE, et al. Maternal inflammatory diet and adverse pregnancy outcomes: Circulating cytokines and genomic imprinting as potential regulators?. Epigenetics. 2017. 12:688-697. doi:10.1080/15592294.2017.1347241. | Intervention/Exposure
156 | McKenzie KM, Dissanayake HU, McMullan R, et al. Quantity and Quality of Carbohydrate Intake during Pregnancy, Newborn Body Fatness and Cardiac Autonomic Control: Conferred Cardiovascular Risk?. Nutrients. 2017. 9:1375. doi:10.3390/nu9121375. | Intervention/Exposure
157 | Melero V, Arnoriaga M, Barabash A, et al. An Early Mediterranean-Based Nutritional Intervention during Pregnancy Reduces Metabolic Syndrome and Glucose Dysregulation Rates at 3 Years Postpartum. Nutrients. 2023. 15. doi:10.3390/nu15143252. | Outcome
158 | Melero V, Assaf-Balut C, de la Torre NG, et al. Benefits of adhering to a mediterranean diet supplemented with extra virgin olive oil and pistachios in pregnancy on the health of offspring at 2 years of age. Results of the san carlos gestational diabetes mellitus prevention study. Journal of Clinical Medicine. 2020. 9. doi:10.3390/jcm9051454. | Data Overlap
159 | Meng Q, Del Rosario I, Sung K, et al. Maternal dietary patterns and placental outcomes among pregnant women in Los Angeles. Placenta. 2023 Dec 5. 145:72-79. doi: 10.1016/j.placenta.2023.12.002. | Outcome
160 | Menichini D, Petrella E, Dipace V, et al. The Impact of an Early Lifestyle Intervention on Pregnancy Outcomes in a Cohort of Insulin-Resistant Overweight and Obese Women. Nutrients. 2020. 12. doi:10.3390/nu12051496. | Intervention/Exposure; Comparator
161 | Micali N, Al Essimii H, Field AE, et al. Pregnancy loss of control over eating: A longitudinal study of maternal and child outcomes. American Journal of Clinical Nutrition. 2018. 108:101-107. doi:10.1093/ajcn/nqy040. | Intervention/Exposure
162 | Minato-Inokawa S, Hayashi I, Nirengi S, et al. Association of Dietary Change during Pregnancy with Large-for-Gestational Age Births: A Prospective Observational Study. J Nutr Sci Vitaminol (Tokyo). 2020. 66:246-254. doi:10.3177/jnsv.66.246. | Intervention/Exposure
163 | Mitku AA, Zewotir T, North D, et al. The differential effect of maternal dietary patterns on quantiles of Birthweight. BMC Public Health. 2020. 20:976. doi:10.1186/s12889-020-09065-x. | Outcome
164 | Mogensen CS, Zingenberg H, Svare J, et al. Gestational weight gain in women with pre-pregnancy overweight or obesity and anthropometry of infants at birth. Frontiers in Pediatrics. 2023. 11. doi:10.3389/fped.2023.1142920. | Intervention/Exposure
165 | Monthé-Drèze C, Rifas-Shiman SL, Aris IM, et al. Maternal diet in pregnancy is associated with differences in child body mass index trajectories from birth to adolescence. Am J Clin Nutr. 2021. 113:895-904. doi:10.1093/ajcn/nqaa398. | Outcome
166 | Morisaki N, Nagata C, Yasuo S, et al. Optimal protein intake during pregnancy for reducing the risk of fetal growth restriction: the Japan Environment and Children’s Study. British Journal of Nutrition. 2018. 120:1432-1440. doi:10.1017/S000711451800291X. | Intervention/Exposure
167 | Mughir HAAR, Jasim BS, Jassim RNKH. Maternal nutritional status and preterm birth. MedicoLegal Update. 2020. 20:747-751. | Intervention/Exposure
168 | Munda A, Starčič Erjavec M, Molan K, et al. Association between pre-pregnancy body weight and dietary pattern with large-for-gestational-age infants in gestational diabetes. Diabetol Metab Syndr. 2019. 11:68. doi:10.1186/s13098-019-0463-5. | Health Status
169 | Mustafa ST, Harding JE, Wall CR, et al. Adherence to Clinical Practice Guideline Recommendations in Women with Gestational Diabetes and Associations with Maternal and Infant Health—A Cohort Study. Nutrients. 2022. 14:1274. doi:10.3390/nu14061274. | Health Status
170 | Myklebust-Hansen T, Aamodt G, Haugen M, et al. Dietary Patterns in women with Inflammatory Bowel Disease and Risk of Adverse Pregnancy Outcomes: Results from The Norwegian Mother and Child Cohort Study (MoBa). Inflamm Bowel Dis. 2017. 24:12-24. doi:10.1093/ibd/izx006. | Health Status
171 | Naja F, Abdulmalik M, Ayoub J, Mahmoud A, Nasreddine L. Dietary patterns and their associations with postpartum weight retention: results of the MINA cohort study. Eur J Nutr. 2024 Jan 5. doi: 10.1007/s00394-023-03305-7. | Outcome
172 | Nakaki A, Crovetto F, Urru A, et al. Effects of Mediterranean diet or mindfulness-based stress reduction on fetal and neonatal brain development: a secondary analysis of a randomized clinical trial. American Journal of Obstetrics and Gynecology MFM. 2023. 5. doi:10.1016/j.ajogmf.2023.101188. | Intervention/Exposure; Data Overlap
173 | Nishihara N, Haruna M, Usui Y, et al. Dietary Intake and Its Association with Birth Outcomes in Women with Nausea and Vomiting during the Second Trimester of Pregnancy: A Prospective Cohort Study in Japan. Nutrients. 2023 Jul 29. 15(15):3383. doi: 10.3390/nu15153383. | Intervention/Exposure
174 | O’Brien CM, Louise J, Deussen A, et al. In Overweight or Obese Pregnant Women, Maternal Dietary Factors are not Associated with Fetal Growth and Adiposity. Nutrients. 2018. 10. doi:10.3390/nu10070870. | Study Design; Outcome
175 | Oostingh EC, de Vos I, Ham AC, et al. No independent associations between preconception paternal dietary patterns and embryonic growth. the Predict Study. Clin Nutr. 2019. 38:2333-2341. doi:10.1016/j.clnu.2018.10.011. | Outcome
176 | Osredkar J, Geršak ŽM, Karas Kuželički N, et al. Association of Zn and Cu Levels in Cord Blood and Maternal Milk with Pregnancy Outcomes among the Slovenian Population. Nutrients. 2022. 14. doi:10.3390/nu14214667. | Intervention/Exposure
177 | Pacyga DC, Talge NM, Gardiner JC, Calafat AM, Schantz SL, Strakovsky RS. Maternal diet quality moderates associations between parabens and birth outcomes. Environ Res. 2022 Aug 11:114078. doi: 10.1016/j.envres.2022.114078. | Outcome
178 | Pacyga DC, Haggerty DK, Gennings C, et al. Interrogating Components of 2 Diet Quality Indices in Pregnancy using a Supervised Statistical Mixtures Approach. American Journal of Clinical Nutrition. 2023. 118:290. doi:10.1016/j.ajcnut.2023.05.020. | Outcome
179 | Pan W, Karatela S, Lu Q, et al. Association of diet quality during pregnancy with maternal glucose metabolism in Chinese women. British Journal of Nutrition. 2023. 130:958. doi:10.1017/S0007114523000107. | Outcome
180 | Papazian T, Salameh P, Abi Tayeh G, et al. Dietary patterns and birth outcomes of healthy Lebanese pregnant women. Front Nutr. 2022 Sep 27. 9:977288. doi: 10.3389/fnut.2022.977288. eCollection 2022. | Outcome
181 | Parisi F, Rousian M, Huijgen NA, et al. Periconceptional maternal ‘high fish and olive oil, low meat’ dietary pattern is associated with increased embryonic growth: The Rotterdam Periconceptional Cohort (Predict) Study. Ultrasound in Obstetrics & Gynecology. 2017. 50:709-716. doi:10.1002/uog.17408. | Outcome
182 | Parisi F, Rousian M, Koning IV, et al. Periconceptional maternal dairy-rich dietary pattern is associated with prenatal cerebellar growth. PLoS One. 2018. 13:e0197901. doi:10.1371/journal.pone.0197901. | Outcome
183 | Parisi F, Rousian M, Steegers-Theunissen RPM, et al. Early first trimester maternal ‘high fish and olive oil and low meat’ dietary pattern is associated with accelerated human embryonic development. Eur J Clin Nutr. 2018. 72:1655-1662. doi:10.1038/s41430-018-0161-7. | Outcome
184 | Parker HW, Tovar A, McCurdy K, et al. Associations between pre-pregnancy BMI, gestational weight gain, and prenatal diet quality in a national sample. PLoS One. 2019. 14:e0224034. doi:10.1371/journal.pone.0224034. | Outcome
185 | Parlapani E, Agakidis C, Karagiozoglou-Lampoudi T, et al. The Mediterranean diet adherence by pregnant women delivering prematurely: association with size at birth and complications of prematurity. J Matern Fetal Neonatal Med. 2019. 32:1084-1091. doi:10.1080/14767058.2017.1399120. | Study Design
186 | Paterson H, Treharne GJ, Horwath C, et al. Intuitive eating and gestational weight gain. Eating Behaviors. 2019. 34. doi:10.1016/j.eatbeh.2019.101311. | Intervention/Exposure
187 | Pathirathna ML, Sekijima K, Sadakata M, et al. Impact of Second Trimester Maternal Dietary Intake on Gestational Weight Gain and Neonatal Birth Weight. Nutrients. 2017. 9. doi:10.3390/nu9060627. | Intervention/Exposure
188 | Pauley AM, Hohman E, Savage JS, et al. Gestational Weight Gain Intervention Impacts Determinants of Healthy Eating and Exercise in Overweight/Obese Pregnant Women. J Obes. 2018. 2018:6469170. doi:10.1155/2018/6469170. | Intervention/Exposure
189 | Pavlikova J, Ambroz A, Honkova K, et al. Maternal Diet Quality and the Health Status of Newborns. Foods. 2022 Dec 2. 11(23):3893. doi: 10.3390/foods11233893. | Intervention/Exposure; Outcome
190 | Peacock A, Hutchinson D, Wilson J, et al. Adherence to the Caffeine Intake Guideline during Pregnancy and Birth Outcomes: A Prospective Cohort Study. Nutrients. 2018. 10:319. doi:10.3390/nu10030319. | Intervention/Exposure
191 | Peacock L, Seed PT, Dalrymple KV, et al. The UK pregnancies better eating and activity trial (UPBEAT); pregnancy outcomes and health behaviours by obesity class. International Journal of Environmental Research and Public Health. 2020. 17:1-17. doi:10.3390/ijerph17134712. | Intervention/Exposure
192 | Pellonperä O, Koivuniemi E, Vahlberg T, et al. Dietary quality influences body composition in overweight and obese pregnant women. Clinical Nutrition. 2019. 38:1613-1619. doi:10.1016/j.clnu.2018.08.029. | Outcome
193 | Peraita-Costa I, Llopis-González A, Perales-Marín A, et al. Maternal profile according to Mediterranean diet adherence and small for gestational age and preterm newborn outcomes. Public Health Nutr. 2021. 24:1372-1384. doi:10.1017/s1368980019004993. | Study Design
194 | Pereira-da-Silva L, Virella D. Which type of maternal dietary polyunsaturated fat affects fetal adiposity?. Kennedy RAK, Mullaney L, O’Higgins AC et al. The relationship between early pregnancy dietary intakes and subsequent birthweight and neonatal adiposity. Journal of Public Health, Dec2018. 40(4): 747-755. Journal of Public Health. 2020. 42:639-639. doi:10.1093/pubmed/fdz048. | Study Design; Publication Status
195 | Petersen JM, Naimi AI, Kirkpatrick SI, et al. Equal Weighting of the Healthy Eating Index-2010 Components May not be Appropriate for Pregnancy. J Nutr. 2022. doi:10.1093/jn/nxac120. | Intervention/Exposure
196 | Pradella F, Leimer B, Fruth A, Queißer-Wahrendorf A, van Ewijk RJ. Ramadan during pregnancy and neonatal health-Fasting, dietary composition and sleep patterns. PLoS One. 2023 Feb 15. 18(2):e0281051. doi: 10.1371/journal.pone.0281051. eCollection 2023. | Study Design; Intervention/Exposure
197 | Probst Y, Sulistyoningrum DC, Netting MJ, et al. Estimated Choline Intakes and Dietary Sources of Choline in Pregnant Australian Women. Nutrients. 2022. 14. doi:10.3390/nu14183819. | Intervention/Exposure; Outcome
198 | Przybysz P, Kruszewski A, Kacperczyk-Bartnik J, Romejko-Wolniewicz E. The Impact of Maternal Plant-Based Diet on Obstetric and Neonatal Outcomes-A Cross-Sectional Study. Nutrients. 2023 Nov 8. 15(22):4717. doi: 10.3390/nu15224717. | Study Design; Temporality
199 | Qin R, Ding Y, Lu Q, et al. Associations of maternal dietary patterns during pregnancy and fetal intrauterine development. Front Nutr. 2022 Sep 15. 9:985665. doi: 10.3389/fnut.2022.985665. eCollection 2022. | Outcome
200 | Raab R, Hoffmann J, Spies M, et al. Are pre- and early pregnancy lifestyle factors associated with the risk of preterm birth? A secondary cohort analysis of the cluster-randomised GeliS trial. BMC Pregnancy Childbirth. 2022. 22:230. doi:10.1186/s12884-022-04513-5. | Intervention/Exposure
201 | Radwan H, Hashim M, Hasan H, et al. Adherence to the Mediterranean diet during pregnancy is associated with lower odds of excessive gestational weight gain and postpartum weight retention: results of the Mother-Infant Study Cohort. Br J Nutr. 2021. 1-12. doi:10.1017/s0007114521002762. | Outcome
202 | Ramos-Levi A, Barabash A, Valerio J, et al. Genetic variants for prediction of gestational diabetes mellitus and modulation of susceptibility by a nutritional intervention based on a Mediterranean diet. Frontiers in Endocrinology. 2022. 13. doi:10.3389/fendo.2022.1036088. | Outcome
203 | Rhee DK, Ji Y, Hong X, et al. Mediterranean-Style Diet and Birth Outcomes in an Urban, Multiethnic, and Low-Income US Population. Nutrients. 2021. 13. doi:10.3390/nu13041188. | Study Design
204 | Roeren M, Kordowski A, Sina C, et al. Inadequate Choline Intake in Pregnant Women in Germany. Nutrients. 2022. 14. doi:10.3390/nu14224862. | Intervention/Exposure; Outcome
205 | Rohatgi KW, Tinius RA, Cade WT, et al. Relationships between consumption of ultra-processed foods, gestational weight gain and neonatal outcomes in a sample of US pregnant women. PeerJ. 2017. 5:e4091. doi:10.7717/peerj.4091. | Intervention/Exposure; Outcome
206 | Roumi Z, Djazayery A, Keshavarz SA. Association Between Infants Anthropometric Outcomes With Maternal AHEI-P and DII Scores. Clin Nutr Res. 2023 May 4. 12(2):116-125. doi: 10.7762/cnr.2023.12.2.116. eCollection 2023 Apr. | Outcome; Confounders
207 | Ruggieri S, Drago G, Panunzi S, et al. The Influence of Sociodemographic Factors, Lifestyle, and Risk Perception on Dietary Patterns in Pregnant Women Living in Highly Contaminated Areas: Data from the NEHO Birth Cohort. Nutrients. 2022 Aug 25. 14(17):3489. doi: 10.3390/nu14173489. | Outcome
208 | Salavati N, Vinke PC, Lewis F, et al. Offspring Birth Weight Is Associated with Specific Preconception Maternal Food Group Intake: Data from a Linked Population-Based Birth Cohort. Nutrients. 2020. 12. doi:10.3390/nu12103172. | Life Stage
209 | Saldiva SRDM, De Arruda Neta ADCP, Teixeira JA, et al. Dietary Pattern Influences Gestational Weight Gain: Results from the ProcriAr Cohort Study-São Paulo, Brazil. Nutrients. 2022 Oct 21. 14(20):4428. doi: 10.3390/nu14204428. | Outcome
210 | Sámano R, Martínez-Rojano H, Ortiz-Hernández L, et al. Dietary and Nutrient Intake, Eating Habits, and Its Association with Maternal Gestational Weight Gain and Offspring’s Birth Weight in Pregnant Adolescents. Nutrients. 2022 Oct 28. 14(21):4545. doi: 10.3390/nu14214545. | Intervention/Exposure
211 | Šarac J, Havaš Auguštin D, Šunić I, et al. Linking infant size and early growth with maternal lifestyle and breastfeeding - the first year of life in the CRIBS cohort. Ann Hum Biol. 2023 Feb. 50(1):332-340. doi: 10.1080/03014460.2023.2224058. | Outcome
212 | Savage JS, Hohman EE, McNitt KM, et al. Uncontrolled Eating during Pregnancy Predicts Fetal Growth: the Healthy Mom Zone Trial. Nutrients. 2019. 11. doi:10.3390/nu11040899. | Intervention/Exposure
213 | Scherer-Adami F, Dutra-Rosolen M, Schedler F, Carreno I, Alves MN. Nutritional status and dietary intake of pregnant women. Rev Salud Publica (Bogota). 2023 Feb 3. 22(1):27-33. doi: 10.15446/rsap.V22n1.72795. | Study Design; Intervention/Exposure; Outcome
214 | Sen S, Rifas-Shiman SL, Shivappa N, et al. Dietary Inflammatory Potential during Pregnancy Is Associated with Lower Fetal Growth and Breastfeeding Failure: Results from Project Viva. Journal of Clinical Chiropractic Pediatrics. 2017. 16:1381-1381. doi:10.3945/jn.115.225581. | Intervention/Exposure
215 | Shakeri M, Jafarirad S, Amani R, et al. A longitudinal study on the relationship between mother’s personality trait and eating behaviors, food intake, maternal weight gain during pregnancy and neonatal birth weight. Nutrition Journal. 2020. 19. doi:10.1186/s12937-020-00584-2. | Intervention/Exposure
216 | Shankar H, Kumar N, Sandhir R, et al. Association of dietary intake below recommendations and micronutrient deficiencies during pregnancy and low birthweight. J Perinat Med. 2019. 47:724-731. doi:10.1515/jpm-2019-0053. | Country
217 | Sheynblyum M, Conlon RPK, Donofry SD, et al. Incorporating Skills for Managing Mood, Stress, and Sleep into a Gestational Weight Gain Intervention. Journal of Contemporary Psychotherapy. 2022. doi:10.1007/s10879-022-09577-0. | Outcome
218 | Shokri-Mashhadi N, Khoshhali M, Heidari-Beni M, Kelishadi R. Association between maternal plasma total antioxidant capacity and dietary antioxidants intake with birth size outcomes. J Trop Pediatr. 2022 Dec 5. 69(1):fmac112. doi: 10.1093/tropej/fmac112. | Intervention/Exposure
219 | Siega-Riz AM, Vladutiu CJ, Butera NM, et al. Preconception Diet Quality Is Associated with Birth Weight for Gestational Age Among Women in the Hispanic Community Health Study/Study of Latinos. J Acad Nutr Diet. 2021. 121:458-466. doi:10.1016/j.jand.2020.09.039. | Life Stage
220 | Silva CFM, Saunders C, Peres W, et al. Effect of ultra-processed foods consumption on glycemic control and gestational weight gain in pregnant with pregestational diabetes mellitus using carbohydrate counting. PeerJ. 2021. 9. doi:10.7717/peerj.10514. | Intervention/Exposure; Health Status
221 | Simmons D, Devlieger R, van Assche A, et al. Effect of Physical Activity and/or Healthy Eating on GDM Risk: the DALI Lifestyle Study. Journal of clinical endocrinology and metabolism. 2017. 102:903-913. doi:10.1210/jc.2016-3455. | Intervention/Exposure
222 | Simões-Wüst AP, Moltó-Puigmartí C, Jansen EH, et al. Organic food consumption during pregnancy and its association with health-related characteristics: the KOALA Birth Cohort Study. Public Health Nutr. 2017. 20:2145-2156. doi:10.1017/s1368980017001215. | Intervention/Exposure
223 | Simpson SA, Coulman E, Gallagher D, et al. Healthy eating and lifestyle in pregnancy (HELP): a cluster randomised trial to evaluate the effectiveness of a weight management intervention for pregnant women with obesity on weight at 12 months postpartum. Int J Obes (Lond). 2021. 45:1728-1739. doi:10.1038/s41366-021-00835-0. | Intervention/Exposure
224 | Skreden M, Hillesund ER, Wills AK, et al. Adherence to the New Nordic Diet during pregnancy and subsequent maternal weight development: a study conducted in the Norwegian Mother and Child Cohort Study (MoBa). Br J Nutr. 2018. 119:1286-1294. doi:10.1017/s0007114518000776. | Outcome
225 | Smit AJP, Hojeij B, Rousian M, et al. A high periconceptional maternal ultra-processed food consumption impairs embryonic growth: The Rotterdam periconceptional cohort. Clinical Nutrition. 2022. 41:1667. doi:10.1016/j.clnu.2022.06.006. | Intervention/Exposure; Outcome
226 | Soares MM, Juvanhol LL, Ribeiro SAV, et al. Proinflammatory maternal diet and early weaning are associated with the inflammatory diet index of Brazilian children (6–12 mo): A pathway analysis. Nutrition. 2023. 105. doi:10.1016/j.nut.2022.111845. | Study Design; Intervention/Exposure
227 | Spadafranca A, Piuri G, Bulfoni C, et al. Adherence to the Mediterranean Diet and Serum Adiponectin Levels in Pregnancy: Results from a Cohort Study in Normal Weight Caucasian Women. Nutrients. 2018. 10. doi:10.3390/nu10070928. | Outcome
228 | Spies HC, Nel M, Walsh CM. Adherence to the Mediterranean Diet of Pregnant Women in Central South Africa: The NuEMI Study. Nutr Metab Insights. 2022 Jun 24. 15:11786388221107801. doi: 10.1177/11786388221107801. eCollection 2022. | Outcome
229 | Starling AP, Sauder KA, Kaar JL, et al. Maternal Dietary Patterns during Pregnancy Are Associated with Newborn Body Composition. J Nutr. 2017. 147:1334-1339. doi:10.3945/jn.117.248948. | Confounders
230 | Strohmaier S, Bogl LH, Eliassen AH, et al. Maternal healthful dietary patterns during peripregnancy and long-term overweight risk in their offspring. Eur J Epidemiol. 2020. 35:283-293. doi:10.1007/s10654-020-00621-8. | Study Design
231 | Tahir MJ, Haapala JL, Foster LP, et al. Higher Maternal Diet Quality during Pregnancy and Lactation Is Associated with Lower Infant Weight-For-Length, Body Fat Percent, and Fat Mass in Early Postnatal Life. Nutrients. 2019. 11. doi:10.3390/nu11030632. | Confounders
232 | Tajirika-Shirai R, Takimoto H, Yokoyama T, et al. Effect of individualised dietary education at medical check-ups on maternal and fetal outcomes in pregnant Japanese women. Asia Pac J Clin Nutr. 2018. 27:607-616. doi:10.6133/apjcn.082017.01. | Intervention/Exposure
233 | Tanner H, Barrett HL, Callaway LK, et al. Consumption of a Low Carbohydrate Diet in Overweight or Obese Pregnant Women Is Associated with Longer Gestation of Pregnancy. Nutrients. 2021. 13:3511-3511. doi:10.3390/nu13103511. | Intervention/Exposure
234 | Taylor CM, Doerner R, Northstone K, et al. Maternal diet during pregnancy and blood cadmium concentrations in an observational cohort of british women. Nutrients. 2020. 12. doi:10.3390/nu12040904. | Outcome
235 | Teo SM, Murrin CM, Mehegan J, et al. Associations between maternal dietary scores during early pregnancy with placental outcomes. Front Nutr. 2023 Feb 8. 10:1060709. doi: 10.3389/fnut.2023.1060709. eCollection 2023. | Outcome
236 | Teruel Camargo J, Taylor MK, Gajewski BJ, Carlson SE, Sullivan DK, Gibbs HD. Higher Diet Quality in Latina Women during Pregnancy May Be Associated with Sociodemographic Factors. Int J Environ Res Public Health. 2022 Oct 26. 19(21):13895. doi: 10.3390/ijerph192113895. | Outcome
237 | Timmermans S, Steegers-Theunissen RP, Vujkovic M, et al. The Mediterranean diet and fetal size parameters: the Generation R Study. Br J Nutr. 2012. 108. | Outcome
238 | Tomaino L, Reyes Suárez D, Reyes Domínguez A, et al. Adherence to Mediterranean diet is not associated with birthweight - Results form a sample of Canarian pregnant women. Nutr Hosp. 2020. 37:86-92. doi:10.20960/nh.02780. | Study Design
239 | Trak-Fellermeier MA, Campos M, Meléndez M, et al. PEARLS randomized lifestyle trial in pregnant Hispanic women with overweight/obesity: gestational weight gain and offspring birthweight. Diabetes Metab Syndr Obes. 2019. 12:225-238. doi:10.2147/dmso.S179009. | Intervention/Exposure
240 | van Zundert S, van der Padt S, Willemsen S, et al. Periconceptional Maternal Protein Intake from Animal and Plant Sources and the Impact on Early and Late Prenatal Growth and Birthweight: The Rotterdam Periconceptional Cohort. Nutrients. 2022. 14. doi:10.3390/nu14245309. | Intervention/Exposure
241 | Vestgaard M, Christensen A, Viggers L, et al. Birth weight and its relation with medical nutrition therapy in gestational diabetes. Archives of Gynecology & Obstetrics. 2017. 296:35-41. doi:10.1007/s00404-017-4396-7. | Outcome
242 | Vulin M, Magušić L, Metzger A-M, et al. Sodium-to-Potassium Ratio as an Indicator of Diet Quality in Healthy Pregnant Women. Nutrients. 2022. 14. doi:10.3390/nu14235052. | Study Design; Intervention/Exposure
243 | Wahi G, Wilson J, Burning M, et al. Impact of Maternal Health Behaviours and Social Conditions on Infant Diet at Age 1-Year: Results from a Prospective Indigenous Birth Cohort in Ontario, Canada. Nutrients. 2022. 14. doi:10.3390/nu14091736. | Outcome
244 | Wang XY, Zhao P, Frolova A, et al. Diet Quality in Pregnancy and the Risk of Fetal Growth Restriction. American Journal of Obstetrics & Gynecology. 2022. 226:S21-S22. doi:10.1016/j.ajog.2021.11.081. | Publication Status
245 | Wei Q, Shi H, Ma X, et al. The impact of maternal stress on offspring birth weight and the mediating effect of dietary patterns: the Shanghai Maternal-Child Pairs Cohort study. J Affect Disord. 2021. 278:643-649. doi:10.1016/j.jad.2020.09.077. | Outcome
246 | Whyte K, Contento I, Wolf R, et al. A Secondary Analysis of Maternal Ultra-Processed Food Intake in Women with Overweight or Obesity and Associations with Gestational Weight Gain and Neonatal Body Composition Outcomes. J Mother Child. 2022. doi:10.34763/jmotherandchild.20212504.d-21-00025. | Outcome
247 | Wiertsema CJ, Mensink-Bout SM, Duijts L, et al. Associations of DASH Diet in Pregnancy With Blood Pressure Patterns, Placental Hemodynamics, and Gestational Hypertensive Disorders. J Am Heart Assoc. 2021. 10:e017503. doi:10.1161/jaha.120.017503. | Outcome
248 | Wilcox S, Liu J, Turner-McGrievy GM, Boutté AK, Wingard E. Effects of a behavioral intervention on physical activity, diet, and health-related quality of life in pregnant women with elevated weight: results of the HIPP randomized controlled trial. Int J Behav Nutr Phys Act. 2022 Dec 9. 19(1):145. doi: 10.1186/s12966-022-01387-w. | Intervention/Exposure; Outcome
249 | Wilcox S, Liu J, Addy CL, et al. A randomized controlled trial to prevent excessive gestational weight gain and promote postpartum weight loss in overweight and obese women: Health In Pregnancy and Postpartum (HIPP). Contemporary Clinical Trials. 2018. 66:51-63. doi:10.1016/j.cct.2018.01.008. | Outcome; Publication Status
250 | Wrottesley SV, Ong KK, Pisa PT, et al. Maternal traditional dietary pattern and antiretroviral treatment exposure are associated with neonatal size and adiposity in urban, black South Africans. Br J Nutr. 2018. 120:557-566. doi:10.1017/s0007114518001708. | Outcome
251 | Wrottesley SV, Prioreschi A, Kehoe SH, et al. A maternal “mixed, high sugar” dietary pattern is associated with fetal growth. Matern Child Nutr. 2020. 16:e12912. doi:10.1111/mcn.12912. | Outcome
252 | Wu W, Tang N, Zeng J, et al. Dietary Protein Patterns during Pregnancy Are Associated with Risk of Gestational Diabetes Mellitus in Chinese Pregnant Women. Nutrients. 2022. 14. doi:10.3390/nu14081623. | Outcome
253 | Yamada P, Paetow A, Chan M, et al. Pregnancy outcomes with differences in grain consumption: a randomized controlled trial. Journal of Perinatal Medicine. 2022. 50:411-418. doi:10.1515/jpm2021-0479. | Intervention/Exposure
254 | Yang W, Han N, Jiao M, et al. Maternal diet quality during pregnancy and its influence on low birth weight and small for gestational age: a birth cohort in Beijing, China. Br J Nutr. 2022. 7:1-34. doi:10.1017/s0007114522000708. | Intervention/Exposure
255 | Yildizli F, Bulduk EO, Bulduk S, et al. Effects of nutrition education on adipocytokines levels in cord blood at birth. Progress in nutrition. 2018. 20:30-37. doi:10.23751/pn.v20i1.6377. | Intervention/Exposure; Comparator
256 | Yisahak SF, Hinkle SN, Mumford SL, et al. Vegetarian diets during pregnancy, and maternal and neonatal outcomes. Int J Epidemiol. 2021. 50:165-178. doi:10.1093/ije/dyaa200. | Intervention/Exposure
257 | Yong HY, Mohd Shariff Z, Mohd Yusof BN, et al. Pre-Pregnancy BMI Influences the Association of Dietary Quality and Gestational Weight Gain: The SECOST Study. Int J Environ Res Public Health. 2019. 16. doi:10.3390/ijerph16193735. | Outcome
258 | Yoshimura M, Fujita M, Shibata A, et al. Association of Eicosapentaenoic and Docosahexaenoic Acid Intake with Low Birth Weight in the Second Trimester: The Japan Pregnancy Eating and Activity Cohort Study. Nutrients. 2023. 15. doi:10.3390/nu15224831. | Intervention/Exposure
259 | Zambrano E, Nathanielsz PW. Relative contributions of maternal Western-type high fat, high sugar diets and maternal obesity to altered metabolic function in pregnancy. Journal of Physiology. 2017. 595:4573-4574. doi:10.1113/JP274392. | Study Design
260 | Zhang B, Xu K, Mi B, et al. Maternal Dietary Inflammatory Potential and Offspring Birth Outcomes in a Chinese Population. J Nutr. 2023 May. 153(5):1512-1523. doi: 10.1016/j.tjnut.2023.03.006. Epub 2023 Apr 4. | Study Design; Temporality
261 | Zhao R, Gao Q, Xiong T, et al. Moderate Freshwater Fish Intake, but Not n-3 Polyunsaturated Fatty Acids, Is Associated with a Reduced Risk of Small for Gestational Age in a Prospective Cohort of Chinese Pregnant Women. Journal of the Academy of Nutrition & Dietetics. 2022. 122:722-722. doi:10.1016/j.jand.2021.10.016. | Intervention/Exposure
262 | Zhu Y. Are you what you eat? Through the lens of prepregnancy plant-based diets and risk of gestational diabetes. Am J Clin Nutr. 2021 Dec 1. 114(6):1892-1893. doi: 10.1093/ajcn/nqab334. | Study Design
263 | Zhu Y, Olsen SF, Mendola P, et al. Maternal consumption of artificially sweetened beverages during pregnancy, and offspring growth through 7 years of age: a prospective cohort study. Int J Epidemiol. 2017. 46:1499-1508. doi:10.1093/ije/dyx095. | Intervention/Exposure
264 | Zulyniak MA, de Souza RJ, Shaikh M, et al. Does the impact of a plant-based diet during pregnancy on birthweight differ by ethnicity?. Proceedings of the Nutrition Society. 2018. 77:1-1. doi:10.1017/S0029665118001362. | Study Design; Publication Status
265 | Zulyniak MA, de Souza RJ, Shaikh M, et al. Ethnic differences in maternal diet in pregnancy and infant eczema. PLoS ONE. 2020. 15. doi:10.1371/journal.pone.0232170. | Outcome