# Appendix 3 Inclusion and exclusion criteria comparison between existing and updated systematic reviews

Table A 3 Inclusion and exclusion criteria comparison between existing^*^ * Raghavan R, Dreibelbis C, Kingshipp BJ, Wong, YP, Terry N, Abrams B, Bartholomew A, Bodnar LM, Gernand A, Rasmussen K, Siega-Riz AM, Stang JS, Casavale KO, Spahn JM, Stoody E. Dietary Patterns before and during Pregnancy and Gestational Age at Birth: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0103. and updated systematic reviews for the research question: What is the relationship between dietary patterns consumed during pregnancy and gestational age at birth?

Category | Existing Review | Updated Review | Change and Rationale
Study design | [underlined: Included]:; - Randomized controlled trials; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; [underlined: Excluded]:; - Non-randomized controlled trials; - Cross-sectional studies; - Case-control studies; - Uncontrolled studies; - Pre-post studies with a control; - Pre-post studies without a control; - Narrative reviews; - Systematic reviews; - Meta-analyses | [underlined: Included]:; - Randomized controlled trials; - Non-randomized controlled trials^†^; † Including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; [underlined: Excluded]:; - Uncontrolled trials^‡^; ‡ Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies | Non-randomized controlled trials, including quasi-experimental and controlled before-and-after studies, were included in the updated review to align with current NESR standards.
Publication date | [underlined: Included]:; - January 1980 – January 2017; [underlined: Excluded]:; - Before January 1980, after January 2017 | [underlined: Included]:; - January 1980 – January 2024^*^; * This review update date range encompasses the original systematic review date range, which included articles published from January 1980 to January 2017; [underlined: Excluded]:; - Before January 1980, after January 2024 | End of the date range is updated to extend from the end of the search in the existing review to the present.
Population: Study participants | [underlined: Included]:; - Human subjects; [underlined: Excluded]:; - Animal and in vitro models | [underlined: Included]:; - Human; [underlined: Excluded]:; - Non-human | No changes other than to wording for clarity.
Population: Life stage | [underlined: Included]:; - At intervention or exposure:; ○ Adolescent girls and women capable of becoming pregnant (15-44 years); ○ Pregnant girls and women (15-44 years) – single and multiple pregnancies; - At outcome:; ○ Pregnant girls and women (15-44 years) – single and multiple pregnancies; [underlined: Excluded]:; - N/A | [underlined: Included]:; - At intervention or exposure and outcome:; ○ Individuals during pregnancy; [underlined: Excluded]:; - At intervention or exposure and outcome:; ○ Individuals before pregnancy; - Individuals during postpartum | Individuals before pregnancy were excluded from the updated review based on 2025 DGAC question prioritization discussions. Minor changes were made to formatting and wording for clarity.
Population: Health Status | [underlined: Included]:; - Studies conducted in generally healthy women of reproductive age, including women in pre/peri-conception and pregnancy; - Studies conducted in samples with elevated chronic disease risk or pregnancy related conditions, or that enroll some subjects with a disease or with health outcome of interest such as:; ○ Anemia; ○ Gestational diabetes; ○ Hypertension; ○ Preeclampsia; ○ Hyperemesis Gravidarum; ○ Previous adverse outcome (e.g., preterm); ○ Obesity; [underlined: Excluded]:; - Pregnancies conceived ONLY using Assisted Reproductive Technologies; - Studies that exclusively enroll subjects with chronic conditions (e.g. hypertension, diabetes) that are not related to the index pregnancy; - Studies that exclusively enroll subjects with a disease or with the health outcome of interest (intermediate or endpoint health outcomes); - Studies done in hospitalized or malnourished subjects, if hospitalization is not related to index pregnancy | [underlined: Included]:; - Studies that [underlined: exclusively] enroll participants not diagnosed with a disease^*^; * Studies that enroll participants who are at risk for chronic disease will be included; - Studies that enroll [underlined: some] participants:; ○ diagnosed with a disease;; ○ with the outcome of interest;; ○ who became pregnant using Assisted Reproductive Technologies;; ○ with multiple gestation pregnancies;; ○ pre- or post-bariatric surgery;; ○ and/or hospitalized for an illness, injury, or surgery; [underlined: Excluded]:; - Studies that [underlined: exclusively] enroll participants:; ○ diagnosed with a disease;^†^; † Studies that exclusively enroll participants with obesity will be included; ○ with the outcome of interest (i.e., studies that aim to treat participants who have already been diagnosed with the outcome of interest);; ○ who became pregnant using Assisted Reproductive Technologies;; ○ with multiple gestation pregnancies;; ○ pre- or post-bariatric surgery;; ○ and/or hospitalized for an illness, injury, or surgery^‡^; ‡ Studies that exclusively enroll participants post-cesarean section will be included | Studies that exclusively enroll participants with obesity are included in the updated review due to its prevalence and relevance as a risk factor for other conditions. All other changes are to formatting and wording for clarity.
Population: Analytic approach | Not specified | [underlined: Included]:; - Studies that enroll both singleton and multiple gestation pregnancies and present uncombined findings; [underlined: Excluded]:; - Studies that enroll both singleton and multiple gestation pregnancies and only present aggregate findings | Criteria were added to the updated review to clarify that studies enrolling participants with both singleton and multiple gestation pregnancies will only be included if the singleton pregnancy findings can be isolated.
Intervention/exposure | [underlined: Included]:; - Studies that provide a description of the dietary pattern(s) (i.e., foods and beverages) consumed by subjects and that methodologically use:; ○ Indices & scores; ○ Cluster or factor analysis; ○ Reduced rank regression; ○ Other methods; [underlined: Excluded]:; - Studies that do not provide a description of the dietary pattern(s) (i.e., foods and beverages) consumed by subjects^*^; * For example, a study would be excluded from the systematic review if the dietary pattern were labeled “vegetarian” but lacked a description of what foods/beverages were consumed as part of that dietary pattern | [underlined: Included]:; - Studies that examine consumption of and/or adherence to a dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed], including, at a minimum, a description of the foods and beverages in the pattern of each intervention/exposure and comparator group; ○ Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials; - Multi-component intervention in which the isolated effect of the dietary pattern on the outcome(s) of interest is provided or can be determined; [underlined: Excluded]:; - Studies that do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed in each intervention/exposure and comparator group); - Multi-component intervention in which the isolated effect of the dietary pattern on the outcome(s) of interest is not analyzed or cannot be determined (e.g., due to multiple intervention components within groups) | Revisions were made to clarify the intent of the intervention/exposure criteria, but do not represent a change in how the criteria were applied.
Comparator | [underlined: Included]:; - Different levels of adherence to a dietary pattern; - Adherence to a different dietary pattern; [underlined: Excluded]:; - N/A | [underlined: Included]:; - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption of and/or adherence to a dietary pattern; [underlined: Excluded]:; - Consumption of and/or adherence to a similar dietary pattern of which only a specific component or food source is different between groups | Revisions were made to clarify the intent of the comparator criteria, but do not represent a change in how the criteria were applied.
Outcome(s) | [underlined: Included]:; - Intermediate outcomes:; ○ Preterm premature rupture of membrane; ○ Preterm labor; - Endpoint outcome:; ○ Gestational age at birth; [underlined: Excluded]:; - N/A | [underlined: Included]:; Preterm birth; [underlined: Excluded]:; - Gestational age at birth measured continuously | Preterm premature rupture of membrane and preterm labor are not outcomes in the updated review based on lack of results in the existing review. Revisions were also made to enable focus on risk of preterm birth, a gestational age outcome of greater public health concern.
Confounders | [underlined: Included]:; - N/A; [underlined: Excluded]:; - N/A | [underlined: Included]:; - Studies that control for one or more of the key confounders listed in the analytic framework.; [underlined: Excluded]:; - Studies that do not control for any of the key confounders listed in the analytic framework. | Criteria were added to enable focus on a stronger body of evidence.
Temporality | [underlined: Included:]; - Studies when the exposure was assessed prior to the outcome; - Studies when exposure and outcome assessment occurred during overlapping time periods, as long as the study explicitly states that the exposure was assessed prior to the outcome; [underlined: Excluded:]; - Studies when the outcome was assessed prior to the exposure; - Studies when exposure and outcome assessment occurred during overlapping time periods and the study does not explicitly state that the exposure was assessed prior to the outcome | - Not specified | Criteria are covered under “Study Design”.
Publication status | [underlined: Included:]; - Studies published in peer-reviewed journals; [underlined: Excluded:]; - Grey literature, including unpublished data, manuscripts, reports, abstracts, conference proceedings | [underlined: Included:]; - Peer-reviewed articles published in research journals; [underlined: Excluded:]; - Non-peer-reviewed articles, unpublished data or manuscripts, pre-prints, reports, editorials, retracted articles, and conference abstracts or proceedings | No changes other than to wording for clarity.
Language | [underlined: Included:]; - Studies published in English; [underlined: Excluded:]; - Studies published in languages other than English | [underlined: Included:]; - Published in English; [underlined: Excluded:]; - Not published in English | No changes other than to wording for clarity.
Country^*^; * The classification of countries on the Human Development Index (HDI) is based on the UN Development Program Human Development Report Office (http://hdr.undp.org/en/data) for the year the study intervention occurred or data were collected. If the study does not report the year(s) in which the intervention/exposure data were collected, the HDI classification for the year of publication is applied. Studies conducted prior to 1990 are classified based on 1990 HDI classifications. If the year is more recent than the available HDI values, then the most recent HDI classifications are used. If a country is not listed in the HDI, then the current country classification from the World Bank is used (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups) | [underlined: Included:]; - Studies conducted in Very High and High Human Development Countries; [underlined: Excluded:]; - Studies conducted in Medium and Low Human Development Countries | [underlined: Included:]; - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected; [underlined: Excluded:]; - Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected | No changes other than to wording for clarity.