# Appendix 2 Conclusion statements from the existing systematic review

Table A 2 Conclusion statements from the existing systematic review for the research question: What is the relationship between dietary patterns consumed during pregnancy and gestational age at birth?

Citation | Conclusion statement and grade
Raghavan R, Dreibelbis C, Kingshipp BJ, Wong, YP, Terry N, Abrams B, Bartholomew A, Bodnar LM, Gernand A, Rasmussen K, Siega-Riz AM, Stang JS, Casavale KO, Spahn JM, Stoody E. Dietary Patterns before and during Pregnancy and Gestational Age at Birth: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0103. | Limited but consistent evidence suggests that certain dietary patterns during pregnancy are associated with a lower risk of preterm birth and spontaneous preterm birth. These protective dietary patterns are higher in vegetables; fruits; whole grains; nuts, legumes and seeds; and seafood (preterm birth, only), and lower in red and processed meats and fried foods.; Grade: Limited