# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
AHEI: Alternative Healthy Eating Index
BMI: Body mass index
DASH: Dietary Approaches to Stop Hypertension
DP: Dietary pattern
EVOO: Extra-virgin olive oil
FPL: Federal poverty level
GDM: Gestational diabetes mellitus
GW: Gestational weeks
HDI: Human Development Index
HDP: Hypertensive Disorders of Pregnancy
HEI: Healthy Eating Index
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
NICHD: Eunice Kennedy Shriver National Institute of Child Health and Development
NRCT: Non-randomized controlled trial
PCS: Prospective cohort study
PICO: Population, Intervention/exposure, Comparator, Outcome
RCT: Randomized controlled trial
U.K.: United Kingdom
U.S.: United States
USDA: United States Department of Agriculture