# References of the articles included in the systematic review

1 Buscemi J, Berlin KS, Rybak TM, . Health Behavior and Weight Changes Among Ethnic and Racial Minority Preschoolers and Their Parents: Associations Across 1 Year. J Pediatr Psychol. Aug 2016;41(7):777–85.26717958
2 Guerrero AD, Chu L, Franke T, Kuo AA. Father Involvement in Feeding Interactions with Their Young Children. American Journal of Health Behavior. 2016;40(2):221–230.26931754
3 Jones LR, Steer CD, Rogers IS, Emmett PM. Influences on child fruit and vegetable intake: sociodemographic, parental and child factors in a longitudinal cohort study. Public Health Nutr. Jul 2010;13(7):1122–30.20196909
4 Lehto R, Vepsäläinen H, Lehtimäki AV, . Effects of the DAGIS randomized controlled trial on home environment and children’s food consumption according to the degree of implementation. BMC Public Health. Dec 5 2022;22(1):2268.36471322
5 Litterbach EK, Zheng M, Campbell KJ, Laws R, Spence AC. Mealtime TV Use Is Associated with Higher Discretionary Food Intakes in Young Australian Children: A Two-Year Prospective Study. Nutrients. Jun 23 2022;14(13)
6 Mou Y, Jansen PW, Raat H, Nguyen AN, Voortman T. Associations of family feeding and mealtime practices with children’s overall diet quality: Results from a prospective population-based cohort. Appetite. May 1 2021;160:105083.33359227
7 Nezami BT, Lytle LA, Ward DS, Ennett ST, Tate DF. Effect of the Smart Moms intervention on targeted mediators of change in child sugar-sweetened beverage intake. Public Health. May 2020;182:193–198.32375100
8 Surjadi FF, Takeuchi DT, Umoren J. Racial and Ethnic Differences in Longitudinal Patterns of Family Mealtimes: Link to Adolescent Fruit and Vegetable Consumption. J Nutr Educ Behav. Mar 2017;49(3):244–249.e1.27993554
9 van Grieken A, Renders CM, van de Gaar VM, Hirasing RA, Raat H. Associations between the home environment and children’s sweet beverage consumption at 2-year follow-up: the ‘Be active, eat right’ study. Pediatr Obes. Apr 2015;10(2):126–33.24903408
10 Wilson TA, Liu Y, Adolph AL, . Behavior Modification of Diet and Parent Feeding Practices in a Community- Vs Primary Care-Centered Intervention for Childhood Obesity. J Nutr Educ Behav. Feb 2019;51(2):150–161.e1.30139562
11 Haire-Joshu D, Elliott MB, Caito NM, . High 5 for Kids: the impact of a home visiting program on fruit and vegetable intake of parents and their preschool children. Prev Med. Jul 2008;47(1):77–82.18486203
12 Hunsaker SL, Jensen CD. Effectiveness of a Parent Health Report in Increasing Fruit and Vegetable Consumption Among Preschoolers and Kindergarteners. J Nutr Educ Behav. May 2017;49(5):380–386.e1.28258819
13 Lee H, Oldewage-Theron W, Dawson JA. Effects of a Theory-Based, Multicomponent eHealth Intervention for Obesity Prevention in Young Children from Low-Income Families: A Pilot Randomized Controlled Study. Nutrients. May 13 2023;15(10)
14 McGowan L, Cooke LJ, Gardner B, Beeken RJ, Croker H, Wardle J. Healthy feeding habits: efficacy results from a cluster-randomized, controlled exploratory trial of a novel, habit-based intervention with parents. Am J Clin Nutr. Sep 2013;98(3):769–77.23864536
15 Mobley AR, Gans KM, Adamsons K, Huedo-Medina TB. Feasibility, Acceptability, and Preliminary Outcomes of a Father-Focused Childhood Obesity Prevention Program for Low-Income Families with Preschool-Age Children. Child Obes. Jan 2023;19(1):13–24.35275734
16 Østbye T, Krause KM, Stroo M, . Parent-focused change to prevent obesity in preschoolers: results from the KAN-DO study. Prev Med. Sep 2012;55(3):188–95.22705016
17 Tabak RG, Tate DF, Stevens J, Siega-Riz AM, Ward DS. Family ties to health program: a randomized intervention to improve vegetable intake in children. J Nutr Educ Behav. Mar-Apr 2012;44(2):166–71.22154131
18 Tovar A, Fox K, Gans KM, . Results from the Strong Families Start at Home/Familias Fuertes Comienzan en Casa: feasibility randomised control trial to improve the diet quality of low-income, predominantly Hispanic/Latinx children. Public Health Nutr. Jan 24 2023;26(4):1–15.36213951
19 Wolfenden L, Wyse R, Campbell E, . Randomized controlled trial of a telephone-based intervention for child fruit and vegetable intake: long-term follow-up. Am J Clin Nutr. Mar 2014;99(3):543–50.24429539
20 Wyse R, Stacey F, Campbell L, . 5-Year Follow-Up of a Telephone Intervention to Increase Fruit and Vegetable Consumption in Preschoolers: The ‘Healthy Habits’ Cluster Randomised Trial. Nutrients. 2020;12(12):3702.33266039
21 Wyse R, Wolfenden L, Bisquera A. Characteristics of the home food environment that mediate immediate and sustained increases in child fruit and vegetable consumption: mediation analysis from the Healthy Habits cluster randomised controlled trial. Int J Behav Nutr Phys Act. Sep 17 2015;12:118.26381609
22 Wyse R, Wolfenden L, Campbell E, . A cluster randomized controlled trial of a telephone-based parent intervention to increase preschoolers’ fruit and vegetable consumption. Am J Clin Nutr. Jul 2012;96(1):102–10.22623749
23 Gingras V, Switkowski KM, Rifas-Shiman SL, Faleschini S, Oken E, Hivert MF. Associations of Early Parental Concerns and Feeding Behaviors with Child’s Diet Quality through Mid-Childhood. Nutrients. Oct 22 2020;12(11)
24 Metcalfe JJ, Fiese BH. Family food involvement is related to healthier dietary intake in preschool-aged children. Appetite. Jul 1 2018;126:195–200.29601922
25 Ip EH, Marshall SA, Arcury TA, . Child Feeding Style and Dietary Outcomes in a Cohort of Latino Farmworker Families. J Acad Nutr Diet. Jul 2018;118(7):1208–1219.28966049
26 Kamdar N, Hughes SO, Chan W, Power TG, Meininger J. Indirect Effects of Food Insecurity on Body Mass Index Through Feeding Style and Dietary Quality Among Low-Income Hispanic Preschoolers. J Nutr Educ Behav. Jul - Aug 2019;51(7):876–884.30975581