# Summary of conclusion statements and grades

The Committee answered the systematic review question, “What is the relationship between parental and caregiver feeding styles and practices during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans?” with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Structured feeding practices

Food parenting practices by caregivers of children ages 2 to 6 years that structure children’s physical and social eating environments (e.g. availability and accessibility of healthy foods, monitoring children’s eating, modeling of healthy eating behaviors, meal routines such as eating together as a family) are associated with higher intake of fruits and vegetables. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

### Controlling feeding practices

A conclusion statement cannot be drawn about the relationship between controlling food parenting practices (e.g. pressure to eat, overt limits on consumption of certain foods) by caregivers of children ages 2 to 6 years and outcomes related to consuming a dietary pattern aligned with the Dietary Guidelines for Americans because there are substantial concerns with consistency in the body of evidence. (Grade: Grade Not Assignable)

### Autonomy Supportive feeding practices

A conclusion statement cannot be drawn about the relationship between food parenting practices by caregivers of children ages 2 to 6 years that provide developmentally appropriate support for children’s autonomy (e.g., responsive feeding, praise, child involvement in food and eating activities) and outcomes related to consuming a dietary pattern aligned with the Dietary Guidelines for Americans because there is not enough evidence available. (Grade: Grade Not Assignable)

### Feeding Styles

A conclusion statement cannot be drawn about the relationship between feeding styles by caregivers of children ages 2 to 6 years and outcomes related to consuming a dietary pattern aligned with the Dietary Guidelines for Americans because there is not enough evidence available. (Grade: Grade Not Assignable)

## Research recommendations

- Conduct research evaluating the role of caregiver feeding styles and practices in children’s dietary outcomes using robust study designs that are adequately powered, specifically prospective cohort studies and controlled trials.
- Conduct research within the U.S. with samples representing diverse populations of caregivers with regard to sex and/or gender, relationship to the child (e.g., parent, grandparent, other relative), income level, race/ethnicity, and different family structures.
- Identify specific food parenting practices that are ‘supportive’ of healthy dietary intake and eating behaviors in children, particularly those reflecting autonomy support. Empirically evaluate the structure of higher-order dimensions of structure, autonomy support, and control.
- Examine the synergistic role of food parenting practices that support children’s healthful dietary intake. It is important to understand how food parenting practices within and across different domains (structure, control, autonomy support) interact and influence child outcomes.
- Refine existing measures and metrics using techniques like cognitive interviewing to develop meaningful tools to assess food parenting practices and feeding styles suitable across populations. While there are numerous questionnaires that assess caregivers’ usual use of food parenting practices, not all are sensitive to the meaning of feeding styles within cultural groups.
- Conduct research on the role of food parenting practices on children’s dietary quality using more precise dietary intake measures.
- Examine proximal outcomes of food parenting, namely effects on children’s eating behaviors and dietary intake of the child, including a wider range of dietary outcomes. Particularly, more studies are needed evaluating overall diet quality as measured by the Healthy Eating Index.
- Examine the potential moderating role of culture, context, and environments on the influence of food parenting on children’s eating behaviors. Research to understand the drivers and interpretation of various approaches to caregiving is critical for identifying strategies to support caregivers in raising children that are responsive to culture, context, environment.
- Examine the impact of time spent away from the caregiver on children’s eating. Studies focused on food parenting should consider other sources of caregiving that influence dietary intake of the child.
- Examine the potential moderating role of differences among children in food motivated and food avoidant behaviors.

Table 9 Evidence examining the relationship between structured feeding practices during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans^a^,^b^

Study and Population Characteristics | Intervention/Exposure and Comparator, Outcome | Significant Results | Non-Significant Results | Confounders, Model Adjustments, Funding
Lehto, 2022^4^; PCS, DAGIS, Finland Analytic N=408 Power Analysis: NRPrimary Aim: To examine whether the parental DOI of the DAGIS intervention had an effect on 3-6-year old children’s food consumption (namely consumption of f/v sugary everyday foods, sugary treats and SSB) and was the effect mediated by a change in the possible home environment mediators of food consumption (the availability of foods, parental role modeling, norms); Caregiver Characteristics; - Parents: 100%; - Age: NR; - Race/Ethnicity: NR; - Education: Parent education level: low: 26.5%, Medium: 47.9%, High: 25.6%; - SEP, Other: NA; Child Characteristics; - Female: 44%; - Baseline Intake: F/V: 285 g/d, SSB: 95 g/d | Exposure and Comparator: Food availability or access (e.g. limited choices/portion size), Modeling, Rules/limits/boundaries (Continuous); CFP Definition: Change in food availability, change in parental role modelling, and change in parental norms relating to children’s food consumption: per questionnaire; Child age at initial exposure measurement: 5.2 (1.0) y (3-6 y); CFP Assessment Method: Questionnaire; Reporting Method: Caregiver self-reported; Outcome(s): fruits and vegetables, SSB; Outcome assessment method: semi-quantitative FFQ developed for DAGIS study; earlier version showed acceptable test-retest reproducibility and validity against 3-day food records; Age(s) at outcome assessment: ~ 6 y | Fruit & Vegetable intake @ ~6y, B (SE); [underlined: Availability:] 44.90 (12.65), p<0.001; [underlined: Parental role modelling:] 7.08 (1.36), p<0.001; [underlined: Norm:] 9.93 (4.09), p=0.02; SSB intake @ ~6y, B (SE); [underlined: Availability:] 18.30 (6.66), p<0.01; [underlined: Parental role modelling:] 11.85 (4.19), p<0.01; [underlined: Norm:] 33.67 (14.01), p=0.02 | | Key confounders accounted for: SEP and/or parental education, child’s sex; Key confounders NOT accounted for: race and/or ethnicity child’s intake at baseline child’s anthropometry at baseline parental BMI; Model adjustments: age, gender, parental education level, baseline value of CFP (availability, parental role modelling, or norm); Funding: Finnish Ministry of Social Affairs and Health, The Academy of Finland, the Paivikki and Sakari Sohlberg Foundation, Signe and Ane Gyllenberg Foundation, Folhalsan Research Center, and the University of Helsinki
Mou, 2021^6^; PCS, Generation R, Netherlands Analytic N=3626Power Analysis: NR Primary Aim: To explorerelationships of parental feeding practices (restriction, pressure toeat, and monitoring) and mealtime practices (meal skipping behaviors and family meal frequency) in early childhood with overall diet quality of children at school age in a population-based cohort.; Caregiver Characteristics; - Mothers: 86.2%; - Age: NR; - Race/Ethnicity: non-Dutch: 29.3%; - Education: Low (no education up to lower vocational training: 28.6%; High (higher vocational training/university: 71.4%); - SEP, Other: <€2200/month: 28.4%; ≥€2200/month: 31.6%; Child Characteristics; - Female: 50.9%; - Baseline Intake: NR | Exposure and Comparator: Pressure to eat, Restriction, Covert control (e.g. monitoring), Meal and snack routine (e.g. meal schedule/atmosphere of meals/distractions/family presence) (Continuous, Categorical); CFP Definition: Restriction, Monitoring, Pressure to eat: per CFQ; Family breakfast and dinner frequency: “how often do you eat breakfast/dinner around the table together with your children”; Child age at initial exposure measurement: median (IQR): 4.0 (4.0. 4.1); CFP Assessment Method: Child Feeding Questionnaire (CFQ); additional items for family meal frequency; Reporting Method: Caregiver self-reported; Outcome(s): Fruits, vegetables, whole grains, SSBs (individual food component scores); Outcome assessment method: Parents completed validated age-specific semi-quantitative FFQ using last 4 wk as reference period. Diet quality was quantified by predefined food-based DQ score based on Dutch dietary recommendations for 8-y old children consisting of 10 components used for this analysis; Age(s) at outcome assessment: Median (IQR): 8.2 (8.0, 8.2) | Fruit component score @ 8y, OR (95% CI); [underlined: Monitoring:] 1.21 (1.12, 1.30); Pressure to eat: 0.87 (0.81, 0.93); [underlined: Family breakfast freq ≤2d/wk vs. every day (ref):] 0.66 (0.56, 0.78); [underlined: Family dinner freq ≤2d/wk vs. every day (ref):] 0.70 (0.69, 0.72); [underlined: Family dinner freq 3-6 d/wk vs. every day (ref):] 0.80 (0.68, 0.95); Vegetable component score @ 8y, OR (95% CI); Monitoring: 1.20 (1.11, 1.28); Pressure to eat: 0.91 (0.85, 0.97); [underlined: Family breakfast freq ≤2d/wk vs. every day (ref):] 0.72 (0.62, 0.84); [underlined: Family dinner freq ≤2d/wk vs. every day (ref):] 0.56 (0.55, 0.57); Whole grains component score @ 8y, OR (95% CI); Monitoring: 1.27 (1.17, 1.39); Pressure to eat: 0.92 (0.83, 1.00); [underlined: Family breakfast freq ≤2d/wk vs. every day (ref):] 0.61 (0.50, 0.76); [underlined: Family dinner freq ≤2d/wk vs. every day (ref):] 0.50 (0.32, 0.79) | Fruit component score @ 8y, OR (95% CI); Restriction: 1.02 (0.95, 1.09); [underlined: Family breakfast freq 3-6 d/wk vs. every day (ref):] 0.92 (0.78, 1.09); Vegetable component score @ 8y, OR (95% CI); Restriction: 0.97 (0.91, 1.04); [underlined: Family breakfast freq 3-6 d/wk vs. every day (ref):] 0.88 (0.76, 1.02); [underlined: Family dinner freq 3-6 d/wk vs. every day (ref):] 0.93 (0.80, 1.09); Whole grains component score @ 8y, OR (95% CI) Restriction: 0.97 (0.89, 1.06); [underlined: Family breakfast freq 3-6 d/wk vs. every day (ref):] 0.86 (0.69, 1.07); [underlined: Family dinner freq 3-6 d/wk vs. every day (ref):] 0.87 (0.69, 1.09); Sugar containing beverages component score @ 8y, OR (95% CI); Monitoring: 0.92 (0.83, 1.03); Pressure to eat: 0.97 (0.87, 1.08); Restriction: 0.97 (0.87, 1.07); [underlined: Family breakfast freq ≤2d/wk vs. every day (ref):] 0.89 (0.69, 1.16); [underlined: Family breakfast freq 3-6 d/wk vs. every day (ref):] 1.01 (0.79, 1.29); [underlined: Family dinner freq ≤2d/wk vs. every day (ref):] 1.51 (0.88, 2.58); [underlined: Family dinner freq 3-6 d/wk vs. every day (ref):] 1.22 (0.95, 1.57) | Key confounders accounted for: SEP and/or parental education, race and/or ethnicity, child’s anthropometry at baseline, child’s sex; Key confounders NOT accounted for: child’s intake at baseline, parental BMI; Model adjustments: child’s sex, age, and energy intake at FFQ assessment, BMI @ 3 y, maternal education, ethnicity, and household income; Funding: Erasmus MC, University Medical Center, Rotterdam, Erasmus University Rotterdam, Netherlands Organization for Health Research and Development, Netherlands Organization for Health Research, Ministry of Health Welfare and Sport and Ministry of Youth and Families.
Nezami, 2020^7^; PCS, Smart Moms, U.S. Analytic N=51 Power Analysis: NR Primary Aim: To test the theoretical and behavioralmediators of the Smart Moms intervention on changes in childsugar sweetened beverage and juice (SSB/juice) consumption; Caregiver Characteristics; - Mothers: 100%; - Age: 36.4 (5.1); - Race/Ethnicity: White: 75%; - Education: NR; - SEP, Other: NR; Child Characteristics; - Female: NR; - Baseline Intake: SSB/juice per day: 14.0 (9.0) ounces | Exposure and Comparator: Rules/limits/boundaries, Food availability or access (e.g. limited choices/portion size) (Continuous); CFP Definition: limit setting: 100% fruit juice: assessed using single item (in the last month, I limited how many servings of 100% fruit juice my child consumed); fruit/vegetable availability: assessed using a measure of whether each of 71 items were present in the home; Child age at initial exposure measurement: 4.1 (0.8) y [3-5 y]; CFP Assessment Method: Questionnaire; Reporting Method: Caregiver self-reported; Outcome(s): SSB; Outcome assessment method: Mothers completed one 24-h recall on their child’s food and beverage intake the day prior. NDSR generated reports of children’s average SSB and 100% juice intake in fluid ounces/day; Age(s) at outcome assessment:~4.5 y | | Child SSB/Juice at 4.5 y (6 month post-intervention), β (95% CI); [underlined: Limit Setting-100% Fruit Juice @ 3 mo post intervention:] 0.04 (−0.20, 0.29), p>0.10; [underlined: Fruit/Vegetable availability @ 3 mo post-intervention:] 0.11 (−0.61, 0.83), p>0.10 | Key confounders accounted for: race and/or ethnicity, child’s intake at baseline; Key confounders NOT accounted for: SEP and/or parental education, child’s anthropometry at baseline, child’s sex, parental BMI; Model adjustments: Maternal race, number of children in the home, whether the child was in childcare/school; Funding: Gillings Dissertation award, Dissertation Completion Fellowship
van Grieken, 2015^9^; PCS, Be active, eat right, Netherlands Analytic N=2047 Power Analysis: NR Primary Aim: To evaluate the association between home environmental characteristics and sweet beverage consumption of 7-y-old children; Caregiver Characteristics; - Female: 90.6%; - Age: 37.1 (4.4); - Race/Ethnicity: Child Ethnicity: Dutch: 86.5%; - Education: Low: 2.7%, Mid-low: 14.7%, Mid-high: 45.2%, High: 37.5%; - SEP, Other: NA; Child Characteristics; - Female: 49.5%; - Baseline Intake: SSB/day: 3.0 (1.4) | Exposure and Comparator: Rules/limits/boundaries, Covert control (e.g. monitoring), Other, Food availability or access (e.g. limited choices/portion size) (Continuous); CFP Definition: Rules: 3 items; monitoring, discouraging, allowing: 3 items; buying: 2 items; availability at home; Child age at initial exposure measurement: 5.7 (0.4) y; CFP Assessment Method: Questionnaire; Reporting Method: Caregiver self-reported; Outcome(s): SSB; Outcome assessment method: Parents indicated how many glasses of sweet beverages the child consumed on a weekday and weekend day using a 10 point scale (none to 9 or more beverages/day); Age(s) at outcome assessment: ~7 y | SSB intake (glasses per day) @ 7 y, β (95% CI); Discouraging: −0.10 (−0.17, −0.03), p<0.01; Not allowing: −0.18 (−0.27, −0.10), p<0.001; [underlined: No sweet beverages in the home:] −0.16 (−0.24, −0.09), p<0.001; High SSB consumption (>2 SSB/d @ 5 & 7 y) vs. low consumption (≤2 SSB/d @ 5 & 7 y) (REF), OR (95% CI); [underlined: Rules:] 0.78 (0.69, 0.89), p<0.001; [underlined: Monitoring:] 0.77 (0.66), 0.89), p<0.001; Not allowing: 0.67 (0.56, 0.79), p<0.001; [underlined: Not buying:] 0.79 (0.68, 0.92), p<0.01; [underlined: No SSB in the house:] 0.61 (0.54, 0.70), p<0.001; More SSB consumption (≤2 SSB/d @ 5 y, ≥2 SSB/d @ 7 y) vs. low consumption (≤2 SSB/d @ 5 & 7 y) (REF), OR (95% CI); [underlined: Rules:] 0.82 (0.70, 0.95), p<0.05; [underlined: No SSB in the house:] 0.70 (0.59, 0.83), p<0.001; Less SSB consumption (≥ SSB/d @ 5 y, ≤ SSB/d @ 7 y) vs. low consumption (≤2 SSB/d @ 5 & 7 y) (REF), OR (95% CI); [underlined: Rules:] 0.82 (0.70, 0.95), p<0.01; [underlined: Monitoring:] 0.80 (0.68, 0.96), p<0.05; Discouraging: 1.24 (1.07, 1.43), p<0.01; Not allowing: 0.76 (0.63, 0.93), p<0.01; [underlined: No SSB in the house:] 0.81 (0.69, 0.93), p<0.01 | SSB intake (glasses per day) @ 7 y, β (95% CI); [underlined: Rules:] −0.04 (−0.10, 0.03), p≥0.05; [underlined: Monitoring:] −0.05 (−0.13, 0.02), p≥0.05; [underlined: Not buying:] −0.06 (−0.14, 0.02), p≥0.05; High SSB consumption (>2 SSB/d @ 5 & 7 y) vs. low consumption (≤2 SSB/d @ 5 & 7 y)(REF), OR (95% CI); Discouraging: 1.01 (0.89, 1.14), p≥0.05; More SSB consumption (≤2 SSB/d @ 5 y, ≥2 SSB/d @ 7 y) vs. low consumption (≤2 SSB/d @ 5 & 7 y)(REF), OR (95% CI); [underlined: Monitoring:] 0.86 (0.71, 1.05), p≥0.05; Discouraging: 1.02 (0.87, 1.21), p≥0.05; Not allowing: 0.88 (0.71, 1.11), p≥0.05; [underlined: Not buying:] 0.94 (0.76, 1.15), p≥0.05; Less SSB consumption vs. low consumption (≤2 SSB/d @ 5 & 7 y) (REF), OR (95% CI); [underlined: Not buying:] 0.84 (0.70, 1.00), p≥0.05 | Key confounders accounted for: child’s sex, race and/or ethnicity, SEP and/or parental education; Key confounders NOT accounted for: child’s intake at baseline, child’s anthropometry at baseline, parental BMI; Model adjustments: child gender, ethnic background, parent education level, parental beliefs (attitude, perceived difficulty, self-confidence) and habit. Child intake at baseline accounted for in LR models only.; Funding: ZonMw (Netherlands Organization for Health Research and Development)
Jones, 2010^3^; PCS, Avon Longitudinal Study, U.K.; Analytic N=7285; Power Analysis: NR; Primary Aim: To examine the sociodemographic, parental, and child factors that predict fruit and vegetable consumption in 7-y-old children; Caregiver Characteristics; - Mothers: 100%; - Age: NR; - Race/Ethnicity: NR; - Education: Low: 18.4%, Medium: 35.6%, High: 46.0%; - SEP, Other: Family Income: <₤200: 16.5%, ₤200-299:26.4%, ₤300-399: 24.6%,₤400+: 32.4%; Child Characteristics; - Female: 49%; - Baseline Intake: NR | Exposure and Comparator: Rules/limits/boundaries (Categorical); CFP Definition: Rules: Single item “Do you have any rules that you try to follow when feeding the family”; Child age at initial exposure measurement: 65 mo; CFP Assessment Method: Questionnaire; Reporting Method: Caregiver self-reported; Outcome(s): Fruits, vegetables; Outcome assessment method: Three 1 d diet records were completed by parent or main carer who were provided with written instructions on how to complete. Diet records were coded by trained nutritionists using DIDO. When portion sizes were not provided, age specific portion size were assigned based on data from NDNS. Fruit and vegetable consumption was calculated by summing the weight of each type of fruit, fruits juice and vegetable consumed (only 1 portion of fruit juice and baked beans and legumes were included, and all potatoes were excluded.; Age(s) at outcome assessment: 7 y | Fruit consumption @ 7 y, B (95% CI); [underlined: Fresh fruit rule, yes vs. no (ref):] 6.90 (5.81, 7.99), p<0.001; Vegetable consumption @ 7 y, B (95% CI); [underlined: Vegetable/salad rule, yes vs. no (ref):] 1.70 (1.22, 2.17), p<0.001 | Vegetable consumption @ 7 y, B (95% CI); [underlined: Cooked meal rule, yes vs no (ref):] 0.28 (−0.27, 0.83), p=0.311 | Key confounders accounted for: child’s sex, SEP and/or parental education; Key confounders NOT accounted for: race and/or ethnicity, child’s intake at baseline, child’s anthropometry at baseline, parental BMI; Model adjustments: Maternal consumption (fruit or vegetables), maternal education, family income, expenditure on food, food expenditure/person, child’s variety of foods, child’s choosiness, child’s enjoyment of food; Funding: European Commission, Quality of Life and Management of Living Resources Programme, and World Cancer Research Fund.
Surjadi, 2017^8^; PCS, Early Childhood Longitudinal Study, U.S.; Analytic N=6503 Power Analysis: NR; Primary Aim: To examine the longitudinal patterns of family mealtimes across racial/ethnic groups and to investigate whether the associations between longitudinal patterns of family mealtimes, baseline family and demographic characteristics, and healthy food consumption in adolescence differ by race/ethnicity; Caregiver Characteristics; - Mothers: NR; - Age: NR; - Race/Ethnicity: White: 70%, Black: 8.8%, Hispanic: 16.6%, Asian: 4.6%; - Education: NR; - SEP, Other: Family socioeconomic status (range −4.75 to 2.75): 0.1 (0.8); Motheremployed full time: 46%; Child Characteristics; - Female: 48%; - Baseline Intake: NR | Exposure and Comparator: Meal and snack routine (e.g. meal schedule/atmosphere of meals/distractions/family presence) (Continuous); CFP Definition: Family mealtimes: number of breakfasts and dinners eaten together by the family in a typical week (range, 0-14); Child age at initial exposure measurement: 5-6 y (kindergarten); CFP Assessment Method: Questionnaire; Reporting Method: Caregiver self-reported; Outcome(s): Fruit and vegetables; Outcome assessment method: Adolescent-reported questionnaire asking about frequency of fruits, green salads, carrots, and other vegetables consumed with the past week; Age(s) at outcome assessment: 13-14 y (8th grade) | Fruit and vegetable consumption (frequency in past week) @ 8th grade, β (SE); [underlined: Family mealtimes, white:] 0.10 (0.05), p<0.05; Fruit and vegetable consumption (frequency in past week) @ 8th grade, β (SE); [underlined: Change in family mealtimes (KG to 8th grade), White:] 0.14 (0.05), p<0.01; [underlined: Change in family mealtimes (KG to 8th grade), Black:] 0.43 (0.20), p<0.05 | Fruit and vegetable consumption (frequency in past week) @ 8th grade, β (SE); [underlined: Family mealtimes, black:] 0.19 (0.10), p<0.10; [underlined: Family mealtimes, Hispanic:] 0.08 (0.07), p≥0.05; [underlined: Family mealtimes, Asian:] 0.01 (0.25), p≥0.05; Fruit and vegetable consumption (frequency in past week) @ 8th grade, β (SE); [underlined: Change in family mealtimes (KG to 8th grade), Hispanic:] 0.20 (0.11), p<0.10; [underlined: Change in family mealtimes (KG to 8th grade), Asian:] 0.15 (0.39), p≥0.05 | Key confounders accounted for: child’s sex, SEP and/or parental education, race and/or ethnicity; Key confounders NOT accounted for: child’s intake at baseline, child’s anthropometry at baseline, parental BMI; Model adjustments: Regular bedtime, child sex, family socioeconomic status; Funding: Principal Investigator Academy for Research and Engagement, Norther Illinois University
Buscemi, 2016^1^; PCS, HH Effectiveness, U.S. Analytic N=590; Power Analysis: NR; Primary Aim: To determine whether parent health behavior changes and feeding practices were associated with child changes in body mass index z-score and related health behaviors over the course of 1 year.; Caregiver Characteristics; - Parents: 100%; - Age: NR; - Race/Ethnicity: Child Ethnicity: African American: 94%, Hispanic/Latino: 4%, Asian:0.5%, Multiracial: 2.5%; - Education: NR; - SEP, Other: Headstart: 100%; Household income <$30,000: 80%; Child Characteristics; - Female: NR; - Baseline Intake: −0.762 (0.105) | Exposure and Comparator: Restriction, Pressure to eat, Covert control (e.g. monitoring) (Continuous); CFP Definition: Restriction, Monitoring, Pressure to eat: per CFQ; Child age at initial exposure measurement: 4.3 (0.5) y [3-5 y]; CFP Assessment Method: Child Feeding Questionnaire (CFQ); Reporting Method: Caregiver self-reported; Outcome(s): Change in Diet Quality; Outcome assessment method: Intake was estimated using combination of in-preschool meal observation and parent-reported 24-hr recall. Data was entered into NDSR and used to measure diet quality (HEI-2005); Age(s) at outcome assessment: ~ 5 y | | Change in diet quality (Baseline to postintervention, 14-wk), Estimate (SE); Change in restriction (baseline to postintervention): −0.011 (0.015), p=0.442; Change in pressure to eat (baseline postintervention): 0.007(0.009), p=0.452; [underlined: Change in monitoring (baseline postintervention):] 0.017 (0.011), p=0.132; Diet quality @ ~5 y, Estimate (SE); Restriction: −0.012 (0.018), p=0.514; Pressure to eat: 0.021 (0.015), p=0.163); [underlined: Monitoring:] 0.000 (0.014), p=0.979 | Key confounders accounted for: child’s intake at baseline, parental BMI, SEP and/or parental education, child’s anthropometry at baseline; Key confounders NOT accounted for: race and/or ethnicity, child’s sex; Model adjustments: Child’s BMIz, diet quality, caloric intake, physicalactivity, screen time, and caregiver BMI, screen time, feeding practices; Funding: NHLBI, NCI
Wilson, 2019^10^; PCS, Mind, Exercise, Nutrition … Do It! (MEND2-5 and MEND), Coordinated Approach to Child Health (CATCH6-12), Next Steps, U.S.; Analytic N=147; Power Analysis: NR; Primary Aim: To evaluate behavior modification of diet and parent feeding practices in childhood obesity interventions; Caregiver Characteristics; - Parent/primary caregiver: 100%; - Age: NR; - Race/Ethnicity: Hispanic: 86%, non-Hispanic black: 12%; - Education: Less than high school: 44%; - SEP, Other: Annual household income <$25,000: 80%; Child Characteristics; - Female: 51%; - Baseline Intake: 59.87 (8.92) | Exposure and Comparator: Pressure to eat, Rules/limits/boundaries, Covert control (e.g. monitoring), Modeling, Other (overt control) (Continuous); CFP Definition: Overt control, discipline, limit setting, monitoring, reinforcement: per PEAS; Covert Control: form of control which cannot be detected by the child; Modeling: per CFPQ; Child age at initial exposure measurement: 4.4 (1.0) y [2-5y]; CFP Assessment Method: The parenting strategies for eating and activity scale (PEAS), Comprehensive Feeding Practice Questionnaire (CFPQ), additional items from Ogden, 2006^*^ (covert control); * Ogden J, Reynolds R, Smith A. Expanding the concept of parental control: a role for overt and covert control in children’s snacking behaviour?. Appetite. 2006;47(1):100–106. doi:10.1016/j.appet.2006.03.330 16682098; Reporting Method: Caregiver self-reported; Outcome(s): HEI-2010; Outcome assessment method: Parents completed the Block Kids 2004 Hispanic FFQ to determine usual dietary intake from 78 food items. Data from the output files was used to calculate HEI-2010 scores.; Age(s) at outcome assessment: ~5 y | HEI-2010 4-5y, β; [underlined: Discipline:] 0.89, p= 0.04; [underlined: Limit setting:] 1.37, p= 0.006; [underlined: Monitoring:] 1.86, p=0.002; Reinforcement: 1.25, p= 0.004; [underlined: Covert control:] 4.35, p= 0.006 | HEI-2010 4-5y, β; [underlined: Modeling:] 1.27, p>0.05; Control: 0.12, p>0.05 | Key confounders accounted for: SEP and/or parental education; race and/or ethnicity; child’s anthropometry at baseline; child’s sex; parental BMI; Key confounders NOT accounted for: child’s intake at baseline; Model adjustments: Child age, sex, Hispanic ethnicity, and weight, maternal BMI, income, education, and community(Houston or Austin); Funding: Centers for Disease Control and Prevention; Michael and SusanDell Foundation; USDA/AgriculturalResearch Service
Litterbach, 2022^5^; PCS, Family Meals with Young Kids, Australia; Analytic N=352; Power Analysis: NR; Primary Aim: To assess prospective associations between TV use during specific mealtimes (breakfast, lunch, dinner, and snacks) and fruit, vegetable, and discretionary food intakes at thesubsequent 2-year follow-up, and to determine if associations were socioeconomically patterned; Caregiver Characteristics; - Mothers: 97%; - Age: NR; - Race/Ethnicity: NR; - Education: Below university equivalent: 26%, University degree: 74%; - SEP, Other: NA; Child Characteristics; - Female: 48%; - Baseline Intake: ≥ 2 serves of fruits per day: 71%, ≥2 serves vegetables per day: 54% | Exposure and Comparator: Meal and snack routine (e.g. meal schedule/atmosphere of meals/distractions/family presence) (Categorical); CFP Definition: Mealtime TV use: Single item, ‘how often does child watch television while eating (each of breakfast/lunch/dinner/snacks)?; Child age at initial exposure measurement: 6 mo −6 y [6mo −1.5 y: 31%, 1.5-<3y: 29%, 3-<6y: 40%]; CFP Assessment Method: Questionnaire; Reporting Method: Caregiver self-reported; Outcome(s): Fruit, vegetable intake; Outcome assessment method: Parents reported on child daily fruit and vegetable intake which were assessed with a single item, ‘how many serves of vegetables does child usually eat per day?’ Fruit and vegetable intake were dichotomized for analysis as <2 and ≥2 serves per day, respectively.; Age(s) at outcome assessment: 2.5 mo −8 y | Daily fruit intake (≥2 Serves/Day) @ 2 y follow-up, OR (95% CI); [underlined: Dinner TV use (University educated only, n=219-264) 1-2 days/wk vs < 1 day/wk (ref):] 0.41 (0.17–1.02), p= 0.05 | Daily vegetable intake (≥2 Serves/Day) @ 2 y follow-up, β (95% CI); [underlined: Daily mealtime TV use (frequency/day):] 0.84 (0.62–1.13), p=0.24; [underlined: Breakfast TV use 1-2 days/wk vs < 1 day/wk (ref):] 0.92 (0.39–2.19), p=0.86; [underlined: 3-7 days/wk vs < 1 day/wk (ref):] 1.00 (0.55–1.84), p=0.99; [underlined: Lunch TV use]; [underlined: 1-2 days/wk vs < 1 day/wk (ref):] 0.77 (0.34–1.71), p=0.52; [underlined: 3-7 days/wk vs < 1 day/wk (ref):] 0.73 (0.33–1.63), p=0.45; [underlined: Dinner TV use]; [underlined: 1-2 days/wk vs < 1 day/wk (ref):] 0.68 (0.35–1.33), p= 0.26; [underlined: 3-7 days/wk vs < 1 day/wk (ref):] 0.56 (0.29–1.10), p= 0.09; [underlined: Snack TV use]; [underlined: 1-2 days/wk vs < 1 day/wk (ref):] 0.78 (0.36–1.70), p=0.54; [underlined: 3-7 days/wk vs < 1 day/wk (ref):] 0.66 (0.36–1.30), p=0.22; Daily fruit intake (≥2 Serves/Day) @ 2 y follow-up, β (95% CI); [underlined: Daily mealtime TV use]; [underlined: (frequency/day):] 0.85 (0.61–1.8), p=0.33; [underlined: Breakfast TV use]; [underlined: 1-2 days/wk vs < 1 day/wk (ref):] 0.96 (0.35–2.58), p=0.93; [underlined: 3-7 days/wk vs < 1 day/wk (ref):] 0.73 (0.37–1.44), p= 0.37; [underlined: Lunch TV use]; [underlined: 1-2 days/wk vs < 1 day/wk (ref):] 0.85 (0.35–2.03), p= 0.71; [underlined: 3-7 days/wk vs < 1 day/wk (ref):] 0.46 (0.20–1.08), p=0.08; [underlined: Dinner TV use]; [underlined: 1-2 days/wk vs < 1 day/wk (ref):] 0.58 (0.28–1.21), p=0.15; [underlined: 3-7 days/wk vs < 1 day/wk (ref):] 0.84 (0.37–1.90), p= 0.66; [underlined: Snack TV use]; [underlined: 1-2 days/wk vs < 1 day/wk (ref):] 0.85 (0.37–1.97), p= 0.71; [underlined: 3-7 days/wk vs < 1 day/wk (ref):] 0.75 (0.36–1.59), p= 0.45 | Key confounders accounted for: SEP and/or parental education, child’s intake at baseline, child’s sex; Key confounders NOT accounted for: race and/or ethnicity, child’s anthropometry at baseline, parental BMI; Model adjustments: Baseline intakes, child age, child gender, location of meals, family meal frequency, interaction between mealtime TV use and mealtime location; Funding: Institute for Physical Activity and Nutrition (IPAN) Seed Funds
Guerrero, 2016^2^; PCS, Early Childhood Longitudinal Study Birth cohort, U.S.; Analytic N=2441; Power Analysis: NR; Primary Aim: To examine the associations of father-child feeding and physical interactions with dietary practices and weight status in children.; Caregiver Characteristics; - Fathers: 100%; - Age: 35 (6.4) y; - Race/Ethnicity: White: 70.5%, Black: 5.2%, Hispanic: 19.7%, Asian: 3%, Other: 1.6%; - Education: < High School: 13.6%, High School: 23.8% College: 24.9%, ≥ Bachelor’s 37.7%; - SEP, Other: Father’s Employment: 35 or more hours: 92.5%, Less than 35 hours: 3.5%, Unemployed: 4%; Under Federal Poverty Line: 11.1%; Child Characteristics; - Female: 48%; - Baseline Intake: Sweetened beverage intake, Never: 31.7%, At least once a week: 68.3% | Exposure and Comparator: Meal and snack routine (e.g. meal schedule/atmosphere of meals/distractions/family presence) (Continuous); CFP Definition: Frequency of father having breakfast or dinner with child in a typical week: single item; Child age at initial exposure measurement: 24 mo; CFP Assessment Method: Questionnaire; Reporting Method: Caregiver self-reported; Outcome(s): SSB; Outcome assessment method: Single item: “How often in the following 7 days did your child drink Soda pop, sports drink, or fruit drinks that are not 100% fruit juice?” Categories for all outcomes were collapsed to approximate the dietary practices recommended by the 2007 Expert Committee Recommendations regarding childhood prevention and management, the literature on fast food intake and family meals, and ease of interpretation.; Age(s) at outcome assessment: 52 (3.9) mo | Sweetened beverage intake @ 48 mo, OR (95% CI); [underlined: Breakfast with father:] 0.93 (0.87–0.99) | Sweetened beverage intake @ 48 mo, OR (95% CI); [underlined: Dinner with father:] NS (data not reported) | Key confounders accounted for: SEP and/or parental education, race and/or ethnicity, child’s sex, parental BMI; Key confounders NOT accounted for: child’s intake at baseline, child’s anthropometry at baseline; Model adjustments: Child sex, child’s age, child’s birth weight status, child care arrangement, child ever breastfed, child age at introduction of solid foods, mother’s weight status, mother’s depression score, mother’s education, mother’s age, number of adults in household over 18, primary language in household, and poverty indicator, father’s employment, education, race.; Funding: US Department of Health and Human Services (HRSA) Maternal and Child Health Research Program; Eunice Kennedy Shriver National Institute of Child Health and Human Development (NICHD)
McGowan, 2013^14^; RCT-Parallel, Poppets Healthy Feeding Habits Intervention, U.K.; Attrition: Intervention: 15%;; Control: 19%; Power Analysis: Power analysis; [n=90 participants from 6 clusters to detect 1.3 points change in automaticity scores at a=0.05, 90% power]; Primary Aim: To test whether a habit-based intervention could increase the automaticity of parental feeding behaviors, and to examine the effects on children’s food intake; Caregiver Characteristics; - Mother: 91.3%, Father: 4.8%, Other: 4%; - Age: 35.3 (6.9); - Race/Ethnicity: Child race/ethnicity: White: 61%, Black: 11%; Asian (Indian or Pakistani): 6%, Other: 22%; - Education: Compulsory schooling or below: 20.7%, Vocational/A/AS levels: 25.6%, Degree level or higher: 53.7%; - SEP, Other: Enrolled in Children’s Centers (equivalent to Head Start): 100%; Living status: Homeowner: 33.9%; Other: 66.1%; Child Characteristics; - Female: 50%; - Baseline Intake: Fruit intake (servings/day): 2.5 (1.2), Vegetable intake (servings/day): 1.8 (1.1), Sweetened drink intake (occasions/day): 1.0 (1.2) | Int: Healthy feeding habits intervention, n=51: researchers delivered sessions over 8 wks with 4 visits to the home. Each visit focused on 1 domain (serving f/v, healthy snacks, and healthy drinks) with messages/tips for habit formation and practical advice specific to each feeding habit.; Control: Control, n= 55: Parents were offered information to improve healthy eating in children plus a supermarket voucher on study completion; Child age at start of intervention: 3.2 (1.1); Intervention Duration: 8 wk; Compliance: Analysis includes parents who completed 4 home visits; Outcome(s): fruits, vegetables, SSB; Outcome assessment method: Parents completed questions “how many servings of fruits [vegetables] does your child typically eat” and “how often does your child have the following drinks, either with or between meals”. Responses on 7-point scale and scored to reflect average number of daily servings/occasions.; Age(s) at outcome assessment: ~ 3 y | Fruit intake (servings/day) Within-group mean change score, SD; [underlined: Intervention group:] 0.5 (1.1), p<0.001; Vegetable intake (servings/day) Within-group mean change score, SD; [underlined: Intervention group:] 0.8 (1.3), p<0.001; Fruit and vegetable intake (servings/day); [underlined: Increased parental automaticity for serving f/v:] r=0.52, p<0.001; SSB intake (occasions/day) Within-group mean change score, SD; [underlined: Intervention group:] −0.6 (0.9), p<0.001; SSB intake (occasions/day); [underlined: Increased parental automaticity for serving healthy drinks:] r=-0.38, p<0.01 | Fruit intake (servings/day) Within-group mean change score, SD; [underlined: Control group:] 0.2 (1.0), p≥0.05; Fruit intake (servings/day) Within-group mean change score, SD; [underlined: Control group:] 0.1 (0.8), p≥0.05; SSB intake (occasions/day) Within-group mean change score, SD; [underlined: Control group:] −0.3 (1.0), p≥0.05 | Key confounders accounted for: child’s intake at baseline, child’s sex; Key confounders NOT accounted for: SEP and/or parental education, race and/or ethnicity, child’s anthropometry at baseline, parental BMI; Model adjustments: baseline levels of each variable (dietary variables), child’s age and sex, clusters; Funding: Cancer Research UK
Wyse, 2015^21^; RCT-cluster, Healthy Habits, Australia; Attrition: Int: 21%, Control: 12%; Power Analysis: NR; Primary Aim: To identify the characteristics of the home food environment that mediatedimmediate and sustained increases in children’s fruit and vegetable consumption following an effective telephone-based parent intervention; Caregiver Characteristics; - Female: 96%; - Age: 35.4 (5.4); - Race/Ethnicity: NR; - Education: University Education: 47%; - SEP, Other: Household income >AU$100,000: 41%; Child Characteristics; - Female: 49%; - Baseline Intake: NR | Int: Intervention, n=208: Parents received 4 30-min phone calls targeting 3 key areas of home food environment: parental role modeling of fruit and vegetable consumption, availability and accessibility of foods in the home, and introducing supportive food routines (such as eating dinner as a family without the TV on).; Control: Control, n=186: Parents were mailed a booklet containing dietary advice for adults and children.; Child age at start of intervention: 4.3 (0.6) y [3-5 y]; Intervention Duration: 4 wk; Compliance: NR; Outcome(s): Fruit and vegetables; Outcome assessment method: Parents completed the fruit and vegetable subscale of the Children’s Dietary Questionnaire (CDQ); Age(s) at outcome assessment: ~ 5 y | Fruit and vegetable consumption score @ 5 y (12 mo post-intervention), β (se); [underlined: Group allocation:] 0.08 (0.04), p=0.03; [underlined: Parent provision @ 2 mo, mediated by parent provision @ 12 mo & child’s F/v consumption @ 2 mo:] 0.24 (0.03), p<0.0001 | | Key confounders accounted for: none; Key confounders NOT accounted for: SEP and/or parental education, race and/or ethnicity, child’s anthropometry at baseline, child’s sex, parental BMI, child’s intake at baseline; Model adjustments: none (final model); Funding: Cancer Institute of New South Wales
Haire-Joshu, 2008^11^; RCT-cluster, High 5 for Kids, U.S.; Attrition: Int: 20%, Control: 22%; Power Analysis: Sample size calculations for .90 power based on methods focused on nested cohort designs; n=16 sites Primary Aim: To test the effectiveness of a home based intervention focused on teaching parents to ensure a positive FV environment for their preschool children and to examine whether changes in parent behavior were associated with improvements in child intake; Caregiver Characteristics; - Mothers: 95%; - Age: <25 y: 27.8%, 25-29 y: 34.7%, 30-34 y: 21. 0%, 35+: 16.5%; - Race/Ethnicity: White: Intervention: 86.3%; Control: 79.7%; - Education: Not high school graduate: 15.9%; High school graduate: 37.7%, Some college: 26.1%, College graduate: 20.3%; - SEP, Other: Annual household income: <$20,000: 29.5%, $20-35,000: 30%, $35-50,000: 13.1%, ≥50,000: 27.5% Employed: 55.9%; Child Characteristics; - Female: 47%; - Baseline Intake: Fruits & vegetable intake: Intervention: 4.91, Control: 4.79 | Int: Intervention (H5-KIDS), n=759: Families received both ‘Parent As Teachers’ (PAT) plus H5-KIDS, targeting the intrapersonal environment of the parent (e.g., knowledge, FV servings), interpersonal interactions between the parent and child (child-feeding practices, FV modeling) and the physical environment (FV availability in the home). Parent educators delivered 4 H5-KIDS home visits, each addressing the core program areas (knowledge, parental modeling of FV intake, noncoercive feeding practices, FV availability). Each visit provided examples of parent-child activities. Intervention also included storybooks that reinforced 1 of the core areas of the H5-kids program and nutrition newsletters with individualized messages for parents.; Control: Control (PAT): n=899, parenting and child development program (nationwide) focused on positive child development through empowering parents as their child’s first and most influential teachers.; Child age at start of intervention: 2-5 y; Intervention Duration: 7 mo (range: 6-11 mo); Compliance: delivered in entirety to 78% of intervention families; Outcome(s): Fruit and vegetables; Outcome assessment method: Parents reported children’s f/v intake during the past 7 days using an FFQ designed for SLU4kids (27 different f/v). Intake over past 7 days was converted into number to times consumed per day for each food item and total fruits (excluding juice), vegetables (excluding fried potatoes), and f/v combined; Age(s) at outcome assessment: 2-5 y | Change in child’s fruit and vegetable consumption (times per day), B; [underlined: Change in FV availability:] 0.10, p=0.01; Fruit & vegetable intake, Intervention effect (Intervention mean change -Control mean change); [underlined: Normal weight children only:] 0.35, p=0.02 | Change in child’s fruit and vegetable consumption (times per day), B; [underlined: Change in FV modeling (times/wk):] 0.01, p=0.27; Change in non-coercive child-feeding practices: −0.003, p=0.96; Fruit intake, Intervention effect (Intervention mean change - Control mean change); [underlined: Total sample:] 0.07, p=0.34; [underlined: Overweight children only:] −0.06, p=0.62; [underlined: Normal weight children only:] − 0.25, p=0.05; Vegetable intake, Intervention effect (Intervention mean change-Control mean change); [underlined: Total sample]: 0.06, p=0.10; [underlined: Overweight children only:] −0.02, p=0.67; [underlined: Normal weight children only:] 0.10, p=0.06; Fruit & vegetable intake, Intervention effect (Intervention mean change - Control mean change); [underlined: Total sample:] 0.12, p=0.20; [underlined: Overweight children only:] −0.10, p=0.48 | Key confounders accounted for: child’s anthropometry at baseline, child’s intake at baseline, SEP and/or parental education; Key confounders NOT accounted for: race and/or ethnicity, child’s sex, parental BMI; Model adjustments: parent’s age, education, child’s baseline f/v intake, parent f/v intake change (times/d), f/v knowledge, and CFP; Funding: National Cancer Institute
Wolfenden, 2014^19^; RCT-Cluster, Healthy Habits, Australia; Attrition: Int: 21%, Control: 12%; Power Analysis: Power analysis; [n=200/group to detect 1.27 difference in f/v subscale scores, a=0.05, 80% power]; Primary Aim: To determine whether the short-term impact of the Healthy Habits intervention onchildren’s fruit and vegetable intake was sustained 12 and 18 months after baseline data collection and to assess the long-term impact of the intervention on noncore food intake.; Caregiver Characteristics; - Female: 95.2%; - Age: ~ 35 y; - Race/Ethnicity: Child ethnicity: Aboriginal and/or Torres Strait Islander: 1%; - Education: University education: ~47%; - SEP, Other: Household income >AU$100,000: ~41%; Child Characteristics; - Female: 51%; - Baseline Intake: Intervention: 15.05 (0.34), Control: 14.51 (0.38) | Int: Intervention (Healthy Habits): n=164, Consisted of 4 30-min telephone contacts delivered weekly over 1 mo as well as resources with information about healthy eating for children. Sought to increase the availability of f/v in the home, encourage supportive family eating routine, and promote parental role modeling of f/v consumption.; Control: Control: n=164, Participants received a copy of the Australian Guide to Healthy Eating with basic nutrition education and recommendations for healthy diet.; Child age at start of intervention: 4.3 (0.6 y; Intervention Duration: 1 month; Compliance: Completed sensitivity analyses with baseline data carried forward for any data missing at follow-up; Completed 4 telephone calls: 87%; Method: Intent to treat; Outcome(s): Fruit and vegetables; Outcome assessment method: Parents completed the fruit and vegetable subscale of the Children’s Dietary Questionnaire (CDQ); Age(s) at outcome assessment: ~6 y | Fruit and vegetable subscale score (CDQ), Intervention vs. Control, Mean (SEM), B (95% CI); [underlined: 12 mo follow-up:] 16.77 (2.7) vs. 14.89 (0.35), 1.61 (0.88, 2.33), p<0.001 | Fruit and vegetable subscale score (CDQ), Intervention vs. Control, Mean (SEM), B (95% CI); [underlined: 18 mo follow-up:] 16.82 (0.30) vs. 15.98 (0.36), 0.51 (−0.17, 1.18), p=0.14 | Key confounders accounted for: SEP and/or parental education, child’s intake at baseline; Key confounders NOT accounted for: race and/or ethnicity, child’s anthropometry at baseline, child’s sex, parental BMI; Model adjustments: Child CDQ score at baseline and clustering within preschools; Funding: Cancer Institute of New South Wales
Wyse, 2012^22^; RCT-cluster, Healthy Habits, Australia; Attrition: Intervention: 16%,; Control: 9%; Power Analysis: n=300 to detect difference of 1.27 in F&V with 80% power at a=0.05; Primary Aim: To assess the efficacy of a telephone-based intervention for parents to increase the fruit and vegetable consumption of their 3- to 5-year-old children.; Caregiver Characteristics; - Female: ~96%; - Age: ~35 y; - Race/Ethnicity: Child ethnicity: Aboriginal and/or Torres Strait Islander: 4.8%; - Education: University education: 45.2%; - SEP, Other: Household income ≥A$100,000: 40.2%; Child Characteristics; - Female: ~48%; - Baseline Intake: No. daily servings of fruit: ~2.2; No. daily servings of vegetables: ~2.0 | Int: Intervention, n=174: Parents received 4 telephone calls over 4 wk as well as a series of instructional resources (guidebook, meal planner, cookbooks). The intervention focuses on introducing new familial norms associated with healthy eating through making changes in the home food environment, providing positive parental role-modeling, and increasing knowledge and skills related to parenting and nutrition. The calls focused on increasing fruit and vegetable availability and accessibility in the home, increasing parental role-modeling of fruit and vegetable consumption, and enhancing supportive food routines around the home, such as eating dinner as a family without the television on. Within content areas, the information provided was tailored based on assessments made during baseline data collection.; Control: Control, n=169: Parents were emailed the Australian Guide to Healthy Eating. They received no further contact until the 2-mo follow-up data collection call.; Child age at start of intervention: 4.3 (0.6) y [3-5 y]; Intervention Duration: 4 wk; Compliance: Members of the research team monitored each interventionist multiple times throughout the intervention delivery period to assess adherence to the intervention protocol; Method: Intent to treat; Outcome(s): Fruit and vegetables; Outcome assessment method: Parents completed the fruit and vegetable subscale of the Children’s Dietary Questionnaire (CDQ); Age(s) at outcome assessment: ~4 y | Fruit and vegetable subscale score (CDQ), Intervention vs. Control, Mean (SEM), B (95% CI); [underlined: 2 mo follow-up:] 17.0 (0.3) vs. 15.4 (0.3), 1.28 (0.54, 2.03), p<0.001; [underlined: 6 mo follow-up:] 17.0 (0.3) vs. 15.9 (0.3), 0.80 (0.12, 1.49), p=0.021 | | Key confounders accounted for: child’s intake at baseline; Key confounders NOT accounted for: SEP and/or parental education, race and/or ethnicity, child’s anthropometry at baseline, child’s sex, parental BMI; Model adjustments: Clustering by preschool, children’s F/V score at baseline; Funding: Cancer Institute of New South Wales
Hunsaker, 2017^12^; RCT-parallel, U.S.; Attrition: Intervention: 0%, Control: 0%; Power Analysis: The authors conducted simulations to estimate the power of the growth model parameters which indicated that the power to detect differences in intercepts and slopes was relatively low for both fruit andvegetable consumption (fruit= 0.14, 0.30; vegetable= 0.07, 0.39).; Primary Aim: To determine the effectiveness of a parent health report in fruit and vegetableconsumption among preschoolers and kindergarteners; Caregiver Characteristics; - Parents: 100%\; - Age: NR; - Race/Ethnicity: White: 89%, Hispanic: 2%, Asian: 3%, Biracial: 7%; - Education: High school/some college: 10%, Bachelor’s degree: 45%, Graduate degree: 45%; - SEP, Other: Monthly income: $6100 (3323); Child Characteristics; - Female: 51%; - Baseline Intake: Fruit: 1.0 serving/day: Vegetables: 0.76 servings/day | Int: Intervention, n=32: Parents were given a parent health report providing information about their child’s fruit and vegetable intake as well as recommendations for how to increase their child’s fruit and vegetable consumption (i.e., detailed list of parent behaviors to increase consumption); Control: Control, n=33: Parents completed initial baseline assessment but received no intervention until after the completion of the 4-wk assessmentChild age at start of intervention: 5 (0.4) y; Intervention Duration: 4 wk; Compliance: NR; Outcome(s): Fruit and vegetables; Outcome assessment method: Parents completed the NCI Fruit and Vegetable Screener Questionnaire; Age(s) at outcome assessment: 5 y | Change in fruit intake (servings per day), slope mean; [underlined: Control group:] (0.94 to 0.76), −0.06, p=0.01; Change in vegetable intake (servings per day), slope mean; [underlined: Intervention group:] (0.76 to 1.41) 0.19, p<0.01 | Change in fruit intake (servings per day), slope mean; [underlined: Intervention group:] −0.03, p=0.21; Change in vegetable intake (servings per day), slope mean; [underlined: Control:] 0.09, p=0.1 | Key confounders accounted for: child’s sex, child’s anthropometry at baseline, child’s intake at baseline; Key confounders NOT accounted for: SEP and/or parental education, race and/or ethnicity, parental BMI; Model adjustments: age, gender, physical activity, BMI percentile, baseline f/v consumption; Funding: NR
Lee, 2023^13^; RCT-parallel, U.S.; Attrition: Control: 17%;; Intervention: 16%; Power Analysis: NR; Primary Aim: To evaluate a theory-based, multicomponent eHealth intervention aimed at improving child health behaviors and parental psychosocial attributes and feeding practices; Caregiver Characteristics; - Mother: 84.9%, Father: 8.2%, Foster mother: 5.5%, Grandmother: 1.4%; - Age: NR; - Race/Ethnicity: Child race/ethnicity: Biracial:36.9%, Hispanic: 23.3%, Non-Hispanic White: 21.9%, Black: 16.4%; Native Hawaiian and other Pacific Islander: 1.4%; - Education: High school: 30.1%, 1 year of college: 17.8%, Bachelor’s degree or equivalent: 13.7%, 2 years of college: 12.3%, Some high school: 12.3%, 3 years of college: 6.8%, Master’s degree: 6.8%; - SEP, Other: Yearly income: $26,436.97 (17,524.52); Child Characteristics; - Female: 56%; - Baseline Intake: (Servings/day) Control: Fruit: 0.47(0.62), Vegetable: 0.44 (0.47);Intervention: Fruit: 0.57 (0.48), Vegetable:0.45 (0.52) | Int: Intervention: [n=37], eHealth intervention, parents received weekly educational videos through a website and weekly reminder text messages with key information for a total of 8 weeks. Topics included: Food groups using MyPlate; Eat More Fruit; Importance of using responsive feeding practices; Tips on shifting non-responsive to responsive feeding practices; Recommended vegetable intake (tips on increasing vegetable intake at home, importance of parent modeling in eating vegetables); Child Physical activity and screen viewing guidelines for toddlers; Eating on A Budget Tips to shop on a budget for fruit and vegetables; Importance of meal planning; Informed Shopper Elements on food labels, health claims, serving size.; Control: Control: [n=36], received a booklet about general nutrition recommendations for children; Child age at start of intervention: 26.52 (8.48) mo [1-3 y]; Intervention Duration: 8 wk; Compliance: NR; Outcome(s): Fruit and vegetable intake; Outcome assessment method: Parents used mobile devices to capture and send digital food photos of their 24-h child’s meals, snacks, and beverages at baseline and post-intervention in real-time with written descriptions of serving sizes, cooking methods, and food labels. Fruit (excluding fruit juices) and vegetable intakes (excluding french fry products) were recorded in daily servings based on food photos.; Age(s) at outcome assessment: 26.52 (8.48) mo [1-3 y] | Fruit intake (servings/day), Between group change score mean (SD); [underlined: Intervention vs. Control:] 0.89 (1.93), p<0.001; Vegetable intake (servings/day), Between group change score mean (SD); [underlined: Intervention vs. Control:] 0.60 (1.64), p<0.001 | | Key confounders accounted for: parental BMI; Key confounders NOT accounted for: SEP and/or parental education, race and/or ethnicity, child’s intake at baseline, child’s anthropometry at baseline, child’s sex; Model adjustments: Location of recruitment, parental BMI; Funding: The Graduate School and Department of Nutritional Sciences at Texas Tech University (partial funding)
Østbye, 2012^16^; RCT-parallel, KAN-DO (Kids and Adults Now — Defeat Obesity!) study, U.S.; Attrition: Intervention: 22%, control: 24%; Power Analysis: n= 200 per arm, the study had 90% powerwhen the true standardized mean arm difference was 0.374.Primary Aim: The primary outcomes for the overall KAN-DO study are change in child diet, physical activity, and sedentarybehavior from baseline to immediately post-intervention (follow-up 1); Caregiver Characteristics; - Mothers: 100%; - Age: Intervention, <30 y: 29.5%, 30–35y: 31%, >35y 39.5%; Control, <30 y: 23%, 30–35y: 40.5%, >35y 36.5%; - Race/Ethnicity: White: 75.25%, Black: 21.25%, Other races: 3%, Hispanic: 4.75%; - Education: High school graduate or less: 11.5%, Some college: 20.25%, college degree: 42%, graduate school: 26.25%; - SEP, Other: Up to $15,000: 10.15%, $15,001–$30,000: 8.9%, $30,001–$45,000: 9.14%, $45,001–$60,000: 15. 23%, $60,001 or more: 56.6%; Child Characteristics; - Female: 44%; - Baseline Intake: Sugary beverage, intervention: 5.02 (0.77), control: 4.64 (0.62); Fruits and vegetables (≥5 vs. <5), intervention: 18.7%, control: 17.9% | Int: Intervention: [n=156], received 8 monthly mailed interactive kits, followed each month by a 20–30- minute telephone coaching session using motivational interviewing techniques. The intervention targeted the dyad’s healthy weight via instruction in parenting styles and skills, techniques for stress management (including emotion regulation), and education about healthy behaviors. Parenting skill instruction emphasized 1) an authoritative parenting style, 2) routines for sleep and mealtimes, 3) a supportive home environment, 4) role modeling of healthy eating and physical activity, and 5) improvement of feeding style. Education about healthy behavior changes in the dyad targeted: decreased intake of sugary drinks and fast food, increased fruit and vegetable consumption, meals prepared at home, moderate-to-vigorous physical activity (MVPA) and decreased sedentary behavior.; Control: Control: [n=152], received monthly newsletters emphasizing pre-reading skills.; Child age at start of intervention: 3.06 (1.0) y; Intervention Duration: 8 mo; Compliance: Per-protocol; Outcome(s): Fruits and vegetables, sugary beverage; Outcome assessment method: Mothers completed two 24-hour recall (multiple pass). Data was entered into NDSR and used to calculate servings of fruits and vegetables and sugary beverages.; Age(s) at outcome assessment: ~4y | | Fruits and vegetables intake (≥5 vs. <5), Change mean; [underlined: Intervention vs. Control:] 3.9% vs. −0.8%, p=0.16; Sugary beverages intake (oz/day), Change mean (se); [underlined: Intervention vs. control]: −1.32 (0.59) vs. 0.69 (1.17), p=0.13 | Key confounders accounted for: child’s intake at baseline; Key confounders NOT accounted for: SEP and/or parental education, race and/or ethnicity, child’s anthropometry at baseline, child’s sex, parental BMI; Model adjustments: child’s intake at baseline; Funding: NIH, NIDDKD
Tabak, 2012^17^; RCT-parallel, Family Ties to Health, U.S.; Attrition: Intervention: 12%, control: 16%; Power Analysis: n=213 families/group to have 80% power todetect significant differences in vegetable intake; Primary Aim: To evaluate a home-based intervention targeted toward parents to improve vegetable intake in preschool-aged children.; Caregiver Characteristics; - Parents: 100%; Female: 88%; - Age: 36.4 (5.4) y; - Race/Ethnicity: Non-Hispanic White: 83%, non-White: 14%; - Education: College or less: 40%, more than college: 61%; - SEP, Other: Income <$50,000: 19%, ≥$50,000: 79%; Child Characteristics; - Female: 63%; - Baseline Intake: Vegetable intake (servings/day), Intervention: 0.8 (0.4), Control: 0.6 (0.4) | Int: Intervention: [n=22], Parents received 2 phone calls and 4 newsletters over 4 months. A registered dietitian conducted calls. The first call addressed vegetable and food issues based on the baseline surveys (the parenting survey and healthy home checklist), the dietitian helped parents select 1 primary target area for improvement from 4 possible options (vegetable availability; picky eating; modeling; family meals). Parents received four 4- page newsletters, 1 per month, with tailored feedback based on data from the self-assessment and phone call (newsletter included content on all 4 topics, but the order and quantity of the content was adjusted based on the parent-identified intervention goal). A second phone call received in the third month encouraged parents to describe successes, use problem solving to overcome barriers, and receive support and encouragement. The final 2 newsletters were sent following the second call.; Control: Control: [n=21]: Parents received 4 non-health/nutrition-related children’s books, 1 per month; Child age at start of intervention:3.6 (0.8) y; Intervention Duration: 4 mo; Compliance: NR; Outcome(s): Vegetable intake; Outcome assessment method: Parents completed the Block Kids FFQ, which was analyzed by the Block Dietary Data Systems.; Age(s) at outcome assessment: ~4 y | | Vegetable intake (servings/day), β (SE); [underlined: Adjusted for group (intervention/control), baseline intake, age:] 0.1 (0.2), p=0.61; Vegetable intake (servings/day), β (SE); [underlined: Adjusted for group (intervention/control), baseline intake, child age:] 0.1 (0.2), p=0.61 | Key confounders accounted for: child’s intake at baseline; Key confounders NOT accounted for: SEP and/or parental education, race and/or ethnicity, child’s anthropometry at baseline, child’s sex, parental BMI; Model adjustments: Age, baseline intake; Funding: Unrestricted grant from ‘‘Get Kids in Action,’’ a partnership between the Gatorade Corporation and the University of North Carolina
Mobley, 2023^15^; RCT-parallel, U.S.; Attrition: Intervention group: 19%, comparison group: 0%; Power Analysis: n=60 with 76% power to detect an effect size of g= 0.30 in fathers’ food-relatedparenting practices as primary outcome; Primary Aim: To determine feasibility, acceptability, and preliminary outcomes of a father-focused childhood obesity prevention program for low-income families with preschool children.; Caregiver Characteristics; - Biological father: 82%, Stepfather/guardian: 4%, Grandfather: 9%, Other: 4%; - Age: 37.2 (12.5) [21–65 y]; - Race/Ethnicity: White: 33%, Black: 40%, Asian: 2%, Other: 25%; Hispanic: 36%, Non-Hispanic: 64%; - Education: Less than high school: 7%, High school or equivalent: 49%, Some college/technical school: 22%, Associate’s degree: 7%, Bachelor’s degree/higher: 15%; - SEP, Other: Unemployed: 13%, Stay at home parent: 4%, Part time: 18%, Full time: 64%; Child Characteristics; - Female: 47%; - Baseline Intake: Intervention, Frequency child eats vegetables: 2.10 (1.0), Soda consumption (times/day): 0.38 (0.66), Sports drink consumption (times/day): 1 (1.3) Comparison, Frequency child eats vegetables: 2.24 (1.1), Soda consumption (times/day): 0.32 (0.65), Sports drink consumption (times/day): 0.77 (0.97) | Int: Intervention: [n=25], 2-hour weekly interactive face-to-face educational sessions at a Head Start center with both fathers and children. First 45 minutes of the session used mini lessons from the parenting and nutrition program ‘Healthy, Happy Families’ (HHF). During this time, child-focused activities adapted from the All 4 Kids program were conducted in separate room. Remainder 2 hour of the session focused on Cooking Matters for Families lessons, which formed the nutrition foundation for the program. Intervention components focused improving the family mealtime environment through nutrition and parent education including structure, roles, and routines in parenting and feeding.; Control: Comparison: [n=14], wait listed group, did not receive intervention.; Child age at start of intervention:3.9 (0.7) y; Intervention Duration: 8 wk; Compliance: Program attendance: (intervention): 0 sessions: 19%, 1 session: 13%, 2 sessions: 10%, 3sessions: 3%, 4 sessions: 10%, 5sessions: 16%, 6 sessions: 10%, 7sessions: 13%, 8 sessions: 6%; Outcome(s): Vegetable frequency and variety, soda consumption, sports drink consumption; Outcome assessment method: Fathers completed Townsend’s Healthy Kids Questionnaire (45-item) to assess dietary behaviors (vegetable intake and sweetened beverage frequency).; Age(s) at outcome assessment: ~4 y | Frequency of vegetable intake, Hedges’ G Effect size, (95% CI); [underlined: Intervention vs. comparison:] 0.13 (−0.55, 0.81), p=0.07 | Child eats more than 1 kind of vegetable, Hedges’ G Effect size, (95% CI); [underlined: Intervention vs. comparison:] 0.23 (−0.45, 0.90), p=0.17; Soda consumption (times/day), Hedges’ G Effect size, (95% CI)Intervention vs. comparison: 0.29 (−0.96,0.39), p=0.66; Sports drink consumption (times/day), Hedges’ G Effect size, (95% CI); [underlined: Intervention vs. comparison:] 0.17 (−0.84,0.49), p=0.65 | Key confounders accounted for: child’s intake at baseline; Key confounders NOT accounted for: SEP and/or parental education, race and/or ethnicity, child’s anthropometry at baseline, child’s sex, parental BMI; Model adjustments: Pre-test difference in outcomes; Funding: the Eunice Kennedy Shriver National Institute of Child Health & Human Development of the NIH
Tovar, 2023^18^; RCT-parallel, Families Start at Home/Familias Fuertes Comienzan en Casa, U.S. Intervention: 27%, control: 46% Power Analysis: Not powered to detect significant differences in component scoresPrimary Aim: To determine the feasibility of the study protocols, recruitment, the acceptability and fidelity of the intervention and its preliminary efficacy on changes in children’s diet quality and food parenting practices compared to an attention control group.; Caregiver Characteristics; - Mother: 90.5%, Father or other: 9.5%; - Age: 34.48 (7.59) y; - Race/Ethnicity: White: 38.1%, Hispanic/Latinx: 87.3%, Multiracial: 17.5%, Unknown: 23.8%, Other: 20.6%; - Education: <8th grade: 14.3%, High school: 36.5%, College: 49.2%; - SEP, Other: Employment status: Full time: 23.8%, Part time: 20.6%, Other: 55.6%; Annual household income: <$25,000: 54%, $25,000–74,999: 31.7%, >$75,000:4.8%, Unknown: 9.5%; Food assistance (SNAP, WIC< Free or Reduced-Price Meals): 81%; Child Characteristics; - Female: 44%; - Baseline Intake: HEI total score: 61.06 Total fruits component: 3.88; Whole fruits component: 3.42; Total vegetables component: 1.77; Whole grains component: 3.89 | Int: Intervention, n=33: 3 monthly home visits (60–75 min) followed by 3 monthly phone calls (30–45 min). The community health worker (CHW) and parent developed a food parenting and nutrition plan based on motivational interviewing. The specific goal(s) focused on food parenting practices (‘how parents interact with children around meals’), and the home food environment, reasons for the plan, potential barriers to completing the plan and some possible solutions (including social supports). A handout with nutrition and food parenting guidance on creating family routines around healthy eating, empowering children to make healthy choices, choosing and preparing healthy family meals and snacks on a budget, meal planning and tips on how to involve children in family meal planning and preparation were handed at each visit. A tailored handout based on child’s appetitive traits using the CEBQ (at baseline) were also provided.; Control: Control, n=30: Parents received an attention-matched intervention about school readiness promotion adapted from R.E.A.D.Y. (Read Educate and Develop Youth). Parents received the same intervention components as the intervention group, pertinent to school readiness instead of nutrition and included video assessment of a parent reading or completing an activity with their child, and 3-monthly phone calls to check in on progress related to their goals, text messages and printed materials.; Child age at start of intervention: 2-5 y; Intervention Duration: 6 mo; Compliance: Adherence: 88% Participant engagement (0=10): 9.7 Read between-visit text messages: 95 %Read mailed handouts: 73 %; Outcome(s): HEI-2015, fruit, vegetable, whole grains; Outcome assessment method: Parents completed two 24-h dietary recalls (multiple-pass approach). The data was collected and analyzed using NDSR software. HEI-2015 total and component scores were derived using the National Cancer Institute simple HEI scoring algorithm method.; Age(s) at outcome assessment: 2-5 y | HEI-2015 total fruits component score, Effect size (Cohen’s δ) (95% CI); Intervention vs control: 0.82 (0.16, 1.47), p<0.05; HEI-2015 whole fruits component score, Effect size (Cohen’s δ) (95% CI); [underlined: Intervention vs control:] 0.83 (0.17, 1.48), p<0.05 | HEI-2015 total score, Effect size (Cohen’s δ) (95% CI); [underlined: Intervention vs control:] −0.04 (−0.67-0.59), p≥0.05; HEI-2015 total vegetables component score, Effect size (Cohen’s δ) (95% CI); [underlined: Intervention vs control:] −0.23 (− 0.86, 0.41), p≥0.05; HEI-2015 whole grains component score, Effect size (Cohen’s δ) (95% CI); [underlined: Intervention vs control:] 0.02 (− 0.61, 0.65), p≥0.05 | Key confounders accounted for: SEP and/or parental education, race and/or ethnicity, child’s anthropometry at baseline, child’s sex, child’s intake at baseline; Key confounders NOT accounted for: parental BMI; Model adjustments: Parental age, marital status, income, race/ethnicity, birth country, years in the USA, household composition, household chaos, child age, gender, BMI, and childcare attendance, baseline values of the corresponding outcome; Funding: National Heart, Lung, and Blood Institute
Wyse, 2020^20^; RCT-Cluster, Healthy Habits, Australia; Attrition: Int: 32%, Control: 52% Power Analysis: n=400 (200 per group) with a=0.05 to detect a difference of 1.27 on F&V-CDQ at 18-month follow-up; Primary Aim: Primary objective was to determine the effectiveness of a telephone-based parent intervention in increasing children’s F&V consumption after approximately 5 years. A secondary objective was to determine the effect of the intervention on parent F&V consumption; Caregiver Characteristics; - Mothers: 95.6%; - Age: 36.2 (4.6) Y; - Race/Ethnicity: Aboriginal &/or Torres Strait Islander: 1.8%; - Education: University education: 53.1%; - SEP, Other: Household income, ≥AU$100,000: 45.7%; Child Characteristics; - Female: 51%; - Baseline Intake: Daily servings of fruit: 2.3 (1.1); Daily servings of vegetables: 2.2 (1.1) | Int: Intervention: [n=127], parents received four 30-min weekly individual telephone support calls. Main domains included increasing F&V availability and accessibility, parental role-modelling of F&V consumption and introducing supportive eating routines (e.g., eating only at set mealtimes, at the table, without the television on). Behavior change techniques including goal setting, goal revision, self-monitoring, intention formation and using prompts or cues were used.; Control: Control: Parents were mailed a printed booklet, “The Australian Guide to Healthy Eating”, that explained the dietary guidelines and ways to meet them.; Child age at start of intervention: 4.3 (0.6) y [3-5 y]; Intervention Duration: 4 wk; Compliance: NR; Outcome(s): Fruits, vegetables; Outcome assessment method:Participants completed F&V subscale of the Children’s Dietary Questionnaire (F&V-CDQ) via telephone.; Age(s) at outcome assessment: 8.5 y | Daily ‘child’ servings of vegetables, Mean group difference @ 5-y follow-up (95% CI); [underlined: Intervention vs. Control:] 0.5 (0.09, 0.9), p=0.02 | F&V-CDQ score, Mean group difference @ 5 y follow-up, (95% CI); [underlined: Intervention vs control:] 1.1 (−0.03, 2.2), p=0.06; Daily ‘child’ servings of fruit, Mean group difference @ 5-y follow-up (95% CI); [underlined: Intervention vs. Control:] 0.2 (−0.2, 0.5), p=0.26 | Key confounders accounted for: child’s intake at baseline, SEP and/or parental education; Key confounders NOT accounted for: race and/or ethnicity, child’s anthropometry at baseline, child’s sex, parental BMI; Model adjustments: Baseline F/V intake, clustering.; Funding: Cancer Institute New South Wales

a Abbreviations: CFP: Caregiver feeding practice; CFQ: Caregiver Feeding Questionnaire; HEI: Healthy Eating Index; FFQ: Food Frequency Questionnaire; NA: Not Applicable; NDSR: Nutrition Data System for Research; NR: Not Reported; PCS: Prospective cohort study; RCT: Randomized controlled trial; SEP: Socioeconomic position; SSB: Sugar sweetened beverage

b Food parenting practices that fall within this bucket are underlined.

Table 10 Risk of bias for observational studies examining the relationship between structured feeding practices during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Lehto, 2022^4^ | HIGH | HIGH | LOW | HIGH | HIGH | SOME CONCERNS | LOW | VERY HIGH
Mou, 2021^6^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Nezami, 2020^7^ | HIGH | HIGH | LOW | HIGH | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
van Grieken, 2015^9^ | SOME CONCERNS | HIGH | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Jones, 2010^3^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Surjadi, 2017^8^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | HIGH | SOME CONCERNS | HIGH
Buscemi, 2016^1^ | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | HIGH | LOW | SOME CONCERNS | HIGH
Wilson, 2019 (Exposure: discipline, limit setting, monitoring, covert control)^10^ | SOME CONCERNS | HIGH | LOW | HIGH | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Wilson, 2019 (Exposure:modeling)^10^ | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Litterbach, 2022^5^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH
Guerrero, 2016^2^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 11 Risk of bias for randomized controlled trials (parallel) examining the relationship between structured feeding practices during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans^a^

Article | Randomization | Deviations from the intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of reported result | Overall
Hunasker, 2017^12^ | LOW | LOW | LOW | HIGH | SOME CONCERNS | HIGH
Lee, 2023^13^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Østbye, 2012^16^ | LOW | LOW | LOW | LOW | LOW | LOW
Tabak, 2012^17^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Mobley, 2023^15^ | LOW | LOW | LOW | HIGH | LOW | HIGH
Tovar, 2023^18^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 12 Risk of bias for randomized controlled trials (cluster) examining the relationship between structured feeding practices and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans^a^

Article | Randomization | Timing of identification and recruitment of individual participants in relation to timing of randomization | Deviations from the intended interventions (effect of assignment to intervention) | Missing outcome data | Outcome measurement | Selection of reported result | Overall
McGowan, 2013^14^ | LOW | HIGH | LOW | LOW | HIGH | SOME CONCERNS | HIGH
Wyse, 2015^21^ | LOW | LOW | LOW | LOW | SOMECONCERNS | SOMECONCERNS | SOMECONCERNS
Haire-Joshu, 2008^11^ | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Wolfenden, 2014^19^ | LOW | LOW | LOW | LOW | SOMECONCERNS | LOW | SOMECONCERNS
Wyse, 2012^22^ | LOW | LOW | LOW | LOW | SOMECONCERNS | LOW | SOMECONCERNS
Wyse, 2020^20^ | LOW | LOW | LOW | LOW | SOMECONCERNS | SOMECONCERNS | SOMECONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 13 Evidence examining the relationship between controlling feeding practices during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans^a^,^b^

Study and Population Characteristics | Intervention/Exposure and Comparator, Outcome | Significant Results | Non-Significant Results | Confounders, Model Adjustments, Funding
Mou, 2021^6^; PCS, Generation R, Netherlands; Analytic N=3626; Power Analysis: NR; Primary Aim: To explorerelationships of parental feeding practices (restriction, pressure to eat, and monitoring) and mealtime practices (meal skipping behaviors and family meal frequency) in early childhood with overall diet quality of children at school age in a population-based cohort.; Caregiver Characteristics; - Mothers: 86.2%; - Age: NR; - Race/Ethnicity: non-Dutch: 29.3%; - Education: Low (no education up to lower vocational training: 28.6%; High (higher vocational training/university: 71.4%); - SEP, Other: <€2200/month: 28.4%; ≥€2200/month: 31.6%; Child Characteristics; - Female: 50.9%; - Baseline Intake: NR | Exposure and Comparator: Pressure to eat, Restriction, Covert control (e.g. monitoring), Meal and snack routine (e.g. meal schedule/atmosphere of meals/distractions/family presence) (Continuous, Categorical); CFP Definition: Restriction, Monitoring, Pressure to eat: per CFQ; Family breakfast and dinner frequency: “how often do you eat breakfast/dinner around the table together with your children”; Child age at initial exposure measurement: median (IQR): 4.0 (4.0. 4.1); CFP Assessment Method: Child Feeding Questionnaire (CFQ); additional items for family meal frequency; Reporting Method: Caregiver self-reported; Outcome(s): Fruits, vegetables, whole grains, SSBs (individual food component scores); Outcome assessment method: Parents completed validated age-specific semi-quantitative FFQ using last 4 wk as reference period. Diet quality was quantified by predefined food-based DQ score based on Dutch dietary recommendations for 8-y old children consisting of 10 components *used for this analysis; Age(s) at outcome assessment: Median (IQR): 8.2 (8.0, 8.2) | Fruit component score @ 8y, OR (95% CI); Monitoring: 1.21 (1.12, 1.30); [underlined: Pressure to eat:] 0.87 (0.81, 0.93); Family breakfast freq ≤2d/wk vs. every day (ref): 0.66 (0.56, 0.78); Family dinner freq ≤2d/wk vs. every day (ref): 0.70 (0.69, 0.72); Family dinner freq 3-6 d/wk vs. every day (ref): 0.80 (0.68, 0.95); Vegetable component score @ 8y, OR (95% CI); Monitoring: 1.20 (1.11, 1.28); [underlined: Pressure to eat:] 0.91 (0.85, 0.97); Family breakfast freq ≤2d/wk vs. every day (ref): 0.72 (0.62, 0.84); Family dinner freq ≤2d/wk vs. every day (ref): 0.56 (0.55, 0.57); Whole grains component score @ 8y, OR (95% CI); Monitoring: 1.27 (1.17, 1.39); [underlined: Pressure to eat:] 0.92 (0.83, 1.00); Family breakfast freq ≤2d/wk vs. every day (ref): 0.61 (0.50, 0.76); Family dinner freq ≤2d/wk vs. every day (ref): 0.50 (0.32, 0.79) | Fruit component score @ 8y, OR (95% CI); [underlined: Restriction:] 1.02 (0.95, 1.09); Family breakfast freq 3-6 d/wk vs. every day (ref): 0.92 (0.78, 1.09); Vegetable component score @ 8y, OR (95% CI); [underlined: Restriction:] 0.97 (0.91, 1.04); Family breakfast freq 3-6 d/wk vs. every day (ref): 0.88 (0.76, 1.02); Family dinner freq 3-6 d/wk vs. every day (ref): 0.93 (0.80, 1.09); Whole grains component score @ 8y, OR (95% CI); [underlined: Restriction:] 0.97 (0.89, 1.06); Family breakfast freq 3-6 d/wk vs. every day (ref): 0.86 (0.69, 1.07); Family dinner freq 3-6 d/wk vs. every day (ref): 0.87 (0.69, 1.09); Sugar containing beverages component score @ 8y, OR (95% CI); Monitoring: 0.92 (0.83, 1.03); [underlined: Pressure to eat:] 0.97 (0.87, 1.08); [underlined: Restriction:] 0.97 (0.87, 1.07); Family breakfast freq ≤2d/wk vs. every day (ref): 0.89 (0.69, 1.16); Family breakfast freq 3-6 d/wk vs. every day (ref): 1.01 (0.79, 1.29); Family dinner freq ≤2d/wk vs. every day (ref): 1.51 (0.88, 2.58); Family dinner freq 3-6 d/wk vs. every day (ref): 1.22 (0.95, 1.57) | Key confounders accounted for: SEP and/or parental education, race and/or ethnicity, child’s anthropometry at baseline, child’s sex; Key confounders NOT accounted for: child’s intake at baseline, parental BMI; Model adjustments: child’s sex, age, and energy intake at FFQ assessment, BMI @ 3 y, maternal education, ethnicity, and household income; Funding: Erasmus MC, University Medical Center, Rotterdam, Erasmus University Rotterdam, Netherlands Organization for Health Research and Development, Netherlands Organization for Health Research, Ministry of Health Welfare and Sport and Ministry of Youth and Families.
van Grieken, 2015^9^; PCS, Be active, eat right, Netherlands; Analytic N=2047; Power Analysis: NR; Primary Aim: To evaluate the association between home environmental characteristics and sweet beverage consumption of 7-y-old children; Caregiver Characteristics; - Female: 90.6%; - Age: 37.1 (4.4); - Race/Ethnicity: Child Ethnicity: Dutch: 86.5%; - Education: Low: 2.7%, Mid-low: 14.7%, Mid-high: 45.2%, High: 37.5%; - SEP, Other: NA; Child Characteristics; - Female: 49.5%; - Baseline Intake: SSB/day: 3.0 (1.4) | Exposure and Comparator: Rules/limits/boundaries, Covert control (e.g. monitoring), Other, Food availability or access (e.g. limited choices/portion size) (Continuous); CFP Definition: Rules: 3 items; monitoring, discouraging, allowing: 3 items; buying: 2 items; availability at home; Child age at initial exposure measurement: 5.7 (0.4) y; CFP Assessment Method: Questionnaire; Reporting Method: Caregiver self-reported; Outcome(s): SSB; Outcome assessment method: Parents indicated how many glasses of sweet beverages the child consumed on a weekday and weekend day using a 10 point scale (none to 9 or more beverages/day); Age(s) at outcome assessment: ~7 | SSB intake (glasses per day) @ 7 y, β (95% CI); [underlined: Discouraging:] −0.10 (−0.17, − 0.03), p<0.01; [underlined: Not allowing:] −0.18 (−0.27, −0.10), p<0.001; No sweet beverages in the home: −0.16 (−0.24, −0.09), p<0.001; High SSB consumption (>2 SSB/d @ 5 & 7 y) vs. low consumption (≤2 SSB/d @ 5 & 7 y)(REF), OR (95% CI); Rules: 0.78 (0.69, 0.89), p<0.001; Monitoring: 0.77 (0.66), 0.89), p<0.001; [underlined: Not allowing:] 0.67 (0.56, 0.79), p<0.001; Not buying: 0.79 (0.68, 0.92), p<0.01; No SSB in the house: 0.61 (0.54, 0.70), p<0.001; More SSB consumption (≤2 SSB/d @ 5 y, ≥2 SSB/d @ 7 y) vs. low consumption (≤2 SSB/d @ 5 & 7 y)(REF), OR (95% CI); Rules: 0.82 (0.70, 0.95), p<0.05; No SSB in the house: 0.70 (0.59, 0.83), p<0.001; Less SSB consumption (≥ SSB/d @ 5 y, ≤ SSB/d @ 7 y) vs. low consumption (≤2 SSB/d @ 5 & 7 y) (REF), OR (95% CI); Rules: 0.82 (0.70, 0.95), p<0.01; Monitoring: 0.80 (0.68, 0.96), p<0.05; [underlined: Discouraging:] 1.24 (1.07, 1.43), p<0.01; [underlined: Not allowing:] 0.76 (0.63, 0.93), p<0.01; No SSB in the house: 0.81 (0.69, 0.93), p<0.01 | SSB intake (glasses per day) @ 7 y, β (95% CI); Rules: −0.04 (−0.10, 0.03), p≥0.05; Monitoring: −0.05 (−0.13, 0.02), p≥0.05; Not buying: −0.06 (−0.14, 0.02), p≥0.05; High SSB consumption (>2 SSB/d @ 5 & 7 y) vs. low consumption (≤2 SSB/d @ 5 &7 y) (REF), OR (95% CI); [underlined: Discouraging:] 1.01 (0.89, 1.14), p≥0.05; More SSB consumption (≤2 SSB/d @ 5 y, ≥2 SSB/d @ 7 y) vs. low consumption (≤2 SSB/d @ 5 & 7 y) (REF), OR (95% CI); Monitoring: 0.86 (0.71, 1.05), p≥0.05; [underlined: Discouraging:] 1.02 (0.87, 1.21), p≥0.05; [underlined: Not allowing:] 0.88 (0.71, 1.11), p≥0.05; Not buying: 0.94 (0.76, 1.15), p≥0.05; Less SSB consumption vs. low consumption (≤2 SSB/d @ 5 & 7 y) (REF), OR (95% CI); Not buying: 0.84 (0.70, 1.00), p≥0.05 | Key confounders accounted for: child’s sex, race and/or ethnicity, SEP and/or parental education; Key confounders NOT accounted for: child’s intake at baseline, child’s anthropometry at baseline, parental BMI; Model adjustments: child gender, ethnic background, parent education level, parental beliefs (attitude, perceived difficulty, self-confidence) and habit. Child intake at baseline accounted for in LR models only.; Funding: ZonMw (Netherlands Organization for Health Research and Development)
Buscemi, 2016^1^; PCS, HH Effectiveness, U.S.; Analytic N=590; Power Analysis: NR; Primary Aim: To determine whether parent health behavior changes and feeding practices were associated with child changes in body mass index z-score and related health behaviors over the course of 1 year.; Caregiver Characteristics; - Parents: 100%; - Age: NR; - Race/Ethnicity: Child Ethnicity: African American: 94%, Hispanic/Latino: 4%, Asian:0.5%, Multiracial: 2.5%; - Education: NR; - SEP, Other: Headstart: 100%; Household income <$30,000: 80%; Child Characteristics; - Female: NR; - Baseline Intake: −0.762 (0.105) | Exposure and Comparator: Restriction, Pressure to eat, Covert control (e.g. monitoring) (Continuous); CFP Definition: Restriction, Monitoring, Pressure to eat: per CFQ; Child age at initial exposure measurement: 4.3 (0.5) y [3-5 y]; CFP Assessment Method: Child Feeding Questionnaire (CFQ); Reporting Method: Caregiver self-reported; Outcome(s): Change in Diet Quality; Outcome assessment method: Intake was estimated using combination of in-preschool meal observation and parent-reported 24- hr recall. Data was entered into NDSR and used to measure diet quality (HEI-2005); Age(s) at outcome assessment: ~ 5 y | | Change in diet quality (Baseline to postintervention, 14-wk), Estimate (SE); [underlined: Change in restriction (baseline to postintervention):] −0.011 (0.015), p=0.442; [underlined: Change in pressure to eat (baseline postintervention):] 0.007 (0.009), p=0.452; Change in monitoring (baseline postintervention): 0.017 (0.011), p=0.132; Diet quality @ ~5 y, Estimate (SE); [underlined: Restriction:] −0.012 (0.018), p=0.514; [underlined: Pressure to eat:] 0.021 (0.015), p=0.163); Monitoring: 0.000 (0.014), p=0.979 | Key confounders accounted for: child’s intake at baseline, parental BMI, SEP and/or parental education, child’s anthropometry at baseline; Key confounders NOT accounted for: race and/or ethnicity, child’s sex; Model adjustments: Child’s BMIz, diet quality, caloric intake, physicalactivity, screen time, and caregiver BMI, screen time, feeding practices; Funding: NHLBI, NCI
Gingras, 2020^23^; PCS, Project Viva, U.S.; Analytic N=1172; Power Analysis: NR; Primary Aim: To examineassociations of parental feeding behaviors and weight-related concerns assessed when the child was 2 years old with the child’s dietary quality in early (~3 y) and mid-childhood (~8 y); Caregiver Characteristics; - Mothers: 100%; - Age: 32.5 (4.8) y; - Race/Ethnicity: Child race/ethnicity: White: 70.9%, Black: 11.3%, Hispanic: 3.1%, Other: 14.8%; - Education: College graduate: 74.1%; - SEP, Other: Household income > $70,000: 65.0%; Child Characteristics; - Female: 50%; - Baseline Intake: YHEI @ 2 y: 55.4 (9.4) | Exposure and Comparator: Restriction, Pressure to eat (Categorical); CFP Definition: Restriction, pressure to eat: modified questions from CFQ; Child age at initial exposure measurement: 2.1 (0.0) y; CFP Assessment Method: Child Feeding Questionnaire (CFQ): modified questions; Reporting Method: Caregiver self-reported; Outcome(s): YHEI, fruits and vegetables, sugar sweetened beverage; Outcome assessment method: In early childhood, mothers completed FFQ (87 items) and in mid-childhood, mothers used Prime-Screen, a dietary screener composed of 18 items asking about frequency of consumption of specific food groups. YHEI scores were determined from FFQ data and Prime Screen data.; Age(s) at outcome assessment:3.2 (0.3) y; 7.9 (0.7) y | SSB (Servings/day) @ 3 y, β (95% CI); [underlined: Restrictive feeding, yes:] −0.17 (− 0.28, −0.06); Fruit Juice (Servings/day) @ 3 y, β (95% CI); [underlined: Pressure to eat, yes:] 0.19 (0.03,; 0.36); [underlined: Sensitivity Analysis]; Youth-HEI total points @ 3 y, β (95% CI); [underlined: Pressure to eat, strongly agree vs. other answer categories (ref):] −1.47 (−2.6, −0.08) | Youth-HEI total points @ 3 y, β (95% CI); [underlined: Pressure to eat, yes:] −0.16 (−1.02, 0.71); [underlined: Restrictive feeding, yes:] 0.75 (− 0.88, 2.39); Youth-HEI total points @ 7 y, β (95% CI); [underlined: Pressure to eat, yes:] −0.60 (−1.73, 0.54); [underlined: Restrictive feeding, yes:] 0.59 (− 1.44, 2.62); Fruits and vegetables (servings/day) @ 3 y, β (95% CI); [underlined: Pressure to eat, yes:] −0.06 (−0.30, 0.17); [underlined: Restrictive feeding, yes:] 0.23 (− 0.21, 0.68); Fruits and vegetables (servings/day) @ 7 y, β (95% CI); [underlined: Pressure to eat, yes:] −0.13 (−0.31, 0.06); [underlined: Restrictive feeding, yes:] 0.18 (− 0.15, 0.51); SSB (Servings/day) @ 3 y, β (95% CI); [underlined: Pressure to eat, yes:] −0.05 (−0.10, 0.01); SSB (Servings/day) @ 7 y, β (95% CI); [underlined: Pressure to eat, yes:] 0.02 (−0.02, 0.06); [underlined: Restrictive feeding, yes:] −0.02 (− 0.10, 0.06); Fruit Juice (Servings/day) @ 3 y, β (95% CI); [underlined: Restrictive feeding, yes:] −0.11 (− 0.43,0.21); [underlined: Sensitivity Analysis]; Youth-HEI total points @ 7 y, β (95% CI); [underlined: Pressure to eat, strongly agree vs. other answer categories (ref):] −1.00 (−2.76, 0.77); Fruits and vegetables (servings/day) @ 3 y, β (95% CI); [underlined: Pressure to eat, strongly agree vs. other answer categories (ref):] −0.23 (−0.62, 0.15); Fruits and vegetables (servings/day) @ 7 y, β (95% CI); [underlined: Pressure to eat, strongly agree vs. other answer categories (ref):] 0.02 (−0.27, 0.31); SSB (servings/day) @ 3 y, β (95% CI); [underlined: Pressure to eat, strongly agree vs. other answer categories (ref):] −0.05 (−0.14, 0.04); SSB (servings/day) @ 7 y, β (95% CI); [underlined: Pressure to eat, strongly agree vs. other answer categories (ref):] −0.00 (−0.07, 0.06); Fruit Juice (servings/day) @ 3 y, β (95% CI); [underlined: Pressure to eat, strongly agree vs. other answer categories (ref):] 0.19 (−0.09, 0.46) | Key confounders accounted for: SEP and/or parental education, race and/or ethnicity, child’s intake at baseline, child’s anthropometry at baseline, child’s sex, parental BMI; Key confounders NOT accounted for: none; Model adjustments: Child’s sex and age at outcome assessment, maternal education, marital status, maternal age at inclusion, household income, child’s race/ethnicity, maternal pre-pregnancy BMI, paternal BMI, maternal HEI during pregnancy, child BMIz and YHEI @ 2 y; Funding: NIH
Wilson, 2019^10^; PCS, Mind, Exercise, Nutrition … Do It! (MEND2-5 and MEND), Coordinated Approach to Child Health (CATCH6-12), Next Steps, U.S.; Analytic N=147; Power Analysis: NR; Primary Aim: To evaluate behavior modification of diet and parent feeding practices in childhoodobesity interventions; Caregiver Characteristics; - Parent/primary caregiver: 100%; - Age: NR; - Race/Ethnicity: Hispanic: 86%, non-Hispanic black: 12%; - Education: Less than high school: 44%; - SEP, Other: Annual household income <$25,000: 80%; Child Characteristics; - Female: 51%; - Baseline Intake: 59.87 (8.92) | Exposure and Comparator: Pressure to eat, Rules/limits/boundaries, Covert control (e.g. monitoring), Modeling, Other (overt control) (Continuous); CFP Definition: Overt control, discipline, limit setting, monitoring, reinforcement: per PEAS; Covert Control: form of control which cannot be detected by the child; Modeling: per CFPQ; Child age at initial exposure measurement: 4.4 (1.0) y [2-5y]; CFP Assessment Method: The parenting strategies for eating and activity scale (PEAS), Comprehensive Feeding Practice Questionnaire (CFPQ), additional items from Ogden, 2006^*^ (covert control); * Ogden J, Reynolds R, Smith A. Expanding the concept of parental control: a role for overt and covert control in children’s snacking behaviour?. Appetite. 2006;47(1):100–106. doi:10.1016/j.appet.2006.03.330 16682098; Reporting Method: Caregiver self-reported; Outcome(s): HEI-2010; Outcome assessment method: Parents completed the Block Kids 2004 Hispanic FFQ to determine usual dietary intake from 78 food items. Data from the output files was used to calculate HEI-2010 scores.; Age(s) at outcome assessment: ~5 y | HEI-2010 4-5y, β; Discipline: 0.89, p= 0.04; Limit setting: 1.37, p= 0.006; Monitoring: 1.86, p=0.002; Reinforcement: 1.25, p= 0.004; Covert control: 4.35, p= 0.006 | HEI-2010 4-5y, β; Modeling: 1.27, p>0.05; [underlined: Control:] 0.12, p>0.05 | Key confounders accounted for: SEP and/or parental education; race and/or ethnicity; child’s anthropometry at baseline; child’s sex; parental BMI; Key confounders NOT accounted for: child’s intake at baseline; Model adjustments: Child age, sex, Hispanic ethnicity, and weight, maternal BMI, income, education, and community(Houston or Austin); Funding: Centers for Disease; Control and Prevention; Michael and SusanDell Foundation; USDA/Agricultural Research Service
Haire-Joshu, 2008^11^; RCT-cluster, High 5 for Kids, U.S.; Attrition: Int: 20%, Control: 22% Power Analysis: Sample size calculations for .90 power based on methods focused on nested cohort designs (Koesell T, 1998); n=16 sites; Primary Aim: To test the effectiveness of a home based intervention focused on teaching parents to ensure a positive FV environment for their preschool children and to examine whether changes in parent behavior were associated with improvements in child intake; Caregiver Characteristics; - Mothers: 95%; - Age: <25 y: 27.8%, 25-29 y: 34.7%, 30-34 y: 21. 0%, 35+:16.5%; - Race/Ethnicity: White: Intervention: 86.3%; Control: 79.7%; - Education: Not high school graduate: 15.9%; High school graduate: 37.7%, Some college: 26.1%, College graduate: 20.3%; - SEP, Other: Annual household income: <$20,000: 29.5%, $20- 35,000: 30%, $35-50,000: 13.1%, ≥50,000: 27.5% Employed: 55.9%; Child Characteristics; - Female: 47%; - Baseline Intake: Fruits & vegetable intake: Intervention: 4.91, Control: 4.79 | Int: Intervention (H5-KIDS), n=759: Families received both Parent As Teachers (PAT) plus H5-KIDS, targeting the intrapersonal environment of the parent (e.g., knowledge, FV servings), interpersonal interactions between the parent and child (child-feeding practices, FV modeling) and the physical environment (FV availability in the home). Parent educators delivered 4 H5-KIDS home visits, each addressing the core program areas (knowledge, parental modeling of FV intake, noncoercive feeding practices, FV availability). Each visit provided examples of parent-child activities. Intervention also included storybooks that reinforced 1 of the core areas of the H5-kids program and nutrition newsletters with individualized messages for parents.; Control: Control (PAT): n=899, parenting and child development program (nationwide) focused on positive child development through empowering parents as their child’s first and most influential teachers.; Child age at start of intervention: 2-5 y; Intervention Duration: 7 mo (range: 6-11 mo); Compliance: delivered in entirety to 78% of intervention families; Outcome(s): Fruit and vegetables; Outcome assessment method: Parents reported children’s f/v intake during the past 7 days using an FFQ designed for SLU4kids (27 different f/v). Intake over past 7 days was converted into number to times consumed per day for each food item and total fruits (excluding juice), vegetables (excluding fried potatoes), and f/v combined; Age(s) at outcome assessment: 2-5 y | Change in child’s fruit and vegetable consumption (times per day), B; Change in FV availability: 0.10, p=0.01; Fruit & vegetable intake, Intervention effect (Intervention mean change - Control mean change); [underlined: Normal weight children only:] 0.35, p=0.02 | Change in child’s fruit and vegetable consumption (times per day), B; [underlined: Change in FV modeling (times/wk):] 0.01, p=0.27; [underlined: Change in non-coercive child-feeding practices:] −0.003, p=0.96; Fruit intake, Intervention effect (Intervention mean change-Control mean change); [underlined: Total sample:] 0.07, p=0.34; [underlined: Overweight children only:] −0.06, p=0.62; [underlined: Normal weight children only:] − 0.25, p=0.05; Vegetable intake, Intervention effect; (Intervention mean change-Control mean change); [underlined: Total sample:] 0.06, p=0.10; [underlined: Overweight children only:] −0.02, p=0.67; [underlined: Normal weight children only:] 0.10, p=0.06; Fruit & vegetable intake, Intervention effect (Intervention mean change - Control mean change); [underlined: Total sample:] 0.12, p=0.20; [underlined: Overweight children only:] −0.10, p=0.48 | Key confounders accounted for: child’s anthropometry at baseline, child’s intake at baseline, SEP and/or parental education; Key confounders NOT accounted for: race and/or ethnicity, child’s anthropometry at baseline, child’s sex, parental BMI, race and/or ethnicity, child’s sex, parental BMI; Model adjustments: parent’s age, education, child’s baseline f/v intake, parent f/v intake (times/d), f/v knowledge, change and CFP; Funding: National Cancer Institute

a Abbreviations: CFP: Caregiver feeding practice; CFQ: Caregiver Feeding Questionnaire; HEI: Healthy Eating Index; FFQ: Food Frequency Questionnaire; NDSR: Nutrition Data System for Research; NR: Not Reported; PCS; Prospective cohort study; RCT: Randomized Control Trial; SEP: Socioeconomic position; SSB: Sugar sweetened beverage; YHEI: Youth Healthy Eating Index

b Food parenting practices that fall within this bucket are underlined.

Table 14 Risk of bias for observational studies examining the relationship between controlling feeding practices during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Mou, 2021^6^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Van Grieken, 2015^9^ | SOMECONCERNS | HIGH | LOW | LOW | HIGH | HIGH | SOMECONCERNS | HIGH
Buscemi, 2016^1^ | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | HIGH | LOW | SOME CONCERNS | HIGH
Gingras, 2020^23^ | LOW | HIGH | LOW | LOW | VERY HIGH | SOMECONCERNS | SOMECONCERNS | VERY HIGH
Wilson, 2019^10^ | SOME CONCERNS | HIGH | LOW | HIGH | LOW | SOME CONCERNS | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 15 Risk of bias for randomized controlled trials (cluster) examining the relationship between controlling feeding practices during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans^a^

Article | Randomization | Timing of identification and recruitment of individual participants in relation to timing of randomization | Deviations from the intended interventions (effect of assignment to intervention) | Missing outcome data | Outcome measurement | Selection of reported result | Overall
Haire-Joshu, 2008^11^ | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 16 Evidence examining the relationship between autonomy supportive feeding practices during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans^a^,^b^

Study and Population Characteristics | Intervention/Exposure and Comparator, Outcome | Significant Results | Non-Significant Results | Confounders, Model Adjustments, Funding
Metcalf, 2018^24^; PCS, STRONG Kids 1, U.S. Analytic N=497; Power Analysis: NR; Primary Aim: To examine the influences and correlates of involvement in family food preparation in children at ages 3 and 4.; Caregiver Characteristics; - Parents: 100%; - Age: NR; - Race/Ethnicity: White: 55.9%, Black: 26.4%, Asian: 9.7%, Hispanic/Latino: 6.8%, American Indian/ Native Hawaiian: 1.2%; - Education: NR; - SEP, Other: <$24,999: 30.99%; $25,000-$39,999:14.69%; $40,000$69,999: 18.91%; $70,000-$99,999: 16.90%; >$100,000: 18.51%; Child Characteristics; - Female: 49%; - Baseline Intake: NR | Exposure and Comparator: Child involvement (Continuous); CFP Definition: Family Food involvement: per CFPQ; Child age at initial exposure measurement: 3.25 (0.68) y; CFP Assessment Method: Comprehensive Feeding Practices Questionnaire (CFPQ); Reporting Method: Caregiver self-reported; Outcome(s): vegetables, fresh fruits; Outcome assessment method: Children’s Nutrition Questionnaire; Age(s) at outcome assessment: 4.36 (0.71) y | Fruit intake @ 4 y, β (SE); [underlined: Food involvement:] 0.090 (0.35), p<0.05; Vegetable intake @ 4 y, β (SE); [underlined: Food involvement:] 0.154 (0.031), p<0.001 | Fruit juice intake @ 4 y, β (SE); [underlined: Food involvement:] NS (data not provided); Non-diet soda @ 4 y, β (SE); [underlined: Food involvement:] NS (data not provided) | Key confounders accounted for: SEP and/or parental education, race and/or ethnicity, child’s intake at baseline, child’s sex; Key confounders NOT accounted for: child’s anthropometry at baseline, parental BMI; Model adjustments: Child’s age, sex, race, and parents’ income and work hours, child’s dietary intake at age 3; Funding: Illinois Council for Agriculture Research, University of Illinois Health and Wellness Initiative, USDA, AFRI Childhood Obesity Prevention Challenge
Wilson, 2019^10^; PCS, Mind, Exercise, Nutrition … Do It! (MEND2-5 and MEND), Coordinated Approach to Child Health (CATCH6-12), Next Steps, U.S.; Analytic N=147; Power Analysis: NR; Primary Aim: To evaluate behavior modification of diet and parent feeding practices in childhood obesity interventions; Caregiver Characteristics; - Parent/primary caregiver: 100%; - Age: NR; - Race/Ethnicity: Hispanic: 86%, nonHispanic black: 12%; - Education: Less than high school: 44%; - SEP, Other: Annual household income <$25,000: 80%; Child Characteristics; - Female: 51%; - Baseline Intake: 59.87 (8.92) | Exposure and Comparator: Pressure to eat, Rules/limits/ boundaries, Covert control (e.g. monitoring), Modeling, Other (overt control) (Continuous); CFP Definition: Overt control, discipline, limit setting, monitoring, reinforcement: per PEAS; Covert Control: form of control which cannot be detected by the child; Modeling: per CFPQ; Child age at initial exposure measurement: 4.4 (1.0) y [2-5y]; CFP Assessment Method: The parenting strategies for eating and activity scale (PEAS), Comprehensive; Feeding Practice Questionnaire (CFPQ), additional items from Ogden, 2006^c^ (covert control); Reporting Method: Caregiver self-reported; Outcome(s): HEI-2010; Outcome assessment method: Parents completed the Block Kids 2004 Hispanic FFQ to determine usual dietary intake from 78 food items. Data from the output files was used to calculate HEI-2010 scores.; Age(s) at outcome assessment: ~5 y | HEI-2010 4-5y, β; Discipline: 0.89, p=0.04; Limit setting: 1.37, p=0.006; Monitoring: 1.86, p=0.002; [underlined: Reinforcement:] 1.25, p= 0.004; Covert control: 4.35, p= 0.006 | HEI-2010 4-5y, β Modeling: 1.27, p>0.05; Control: 0.12, p>0.05 | Key confounders accounted for: SEP and/or parental education; race and/or ethnicity; child’s anthropometry at baseline; child’s sex; parental BMI; Key confounders NOT accounted for: child’s intake at baseline; Model adjustments: Child age, sex, Hispanic ethnicity, and weight, maternal BMI, income, education, and community; (Houston or Austin); Funding: Centers for Disease Control and Prevention; Michael and Susan Dell Foundation; USDA/Agricultural Research Service
Lee, 2023^13^; RCT-parallel, U.S.; Attrition: Control: 17%; Intervention: 16%; Power Analysis: NR; Primary Aim: To evaluate a theorybased, multicomponent eHealth intervention aimed at improving child health behaviors and parental psychosocial attributes and feeding practices; Caregiver Characteristics; - Mother: 84.9%, Father: 8.2%, Foster mother: 5.5%, Grandmother: 1.4%; - Age: NR; - Race/Ethnicity: Child race/ethnicity: Biracial:36.9%, Hispanic: 23.3%, NonHispanic White: 21.9%, Black: 16.4%; Native Hawaiian and other Pacific Islander: 1.4%; - Education: High school: 30.1%, 1 year of college: 17.8%, Bachelor’s degree or equivalent: 13.7%, 2 years of college: 12.3%, Some high school: 12.3%, 3 years of college: 6.8%, Master’s degree: 6.8%; - SEP, Other: Yearly income: $26,436.97 (17,524.52); Child Characteristics; - Female: 56%; - Baseline Intake: (Servings/day) Control: Fruit: 0.47 (0.62), Vegetable: 0.44 (0.47); Intervention: Fruit: 0.57 (0.48), Vegetable:0.45 (0.52) | Int: Intervention: [n=37], eHealth intervention, parents received weekly educational videos through a website and weekly reminder text messages with key information for a total of 8 weeks. Topics included: Food groups using MyPlate; Eat More Fruit; Importance of using responsive feeding practices; Tips on shifting non-responsive to responsive feeding practices; Recommended vegetable intake (tips on increasing vegetable intake at home, importance of parent modeling in eating vegetables); Child Physical activity and screen viewing guidelines for toddlers; Eating on A Budget Tips to shop on a budget for fruit and vegetables; Importance of meal planning; Informed Shopper Elements on food labels, health claims, serving size.; Control: Control: [n=36], received a booklet about general nutrition; recommendations for children; Child age at start of intervention: 26.52 (8.48) mo [1-3 y]; Intervention Duration: 8 wk; Compliance: NR; Outcome(s): Fruit and vegetable intake; Outcome assessment method: Parents used mobile devices to capture and send digital food photos of their 24-h child’s meals, snacks, and beverages at baselineand post-intervention in real-time with written descriptions of serving sizes, cooking methods, and food labels. Fruit (excluding fruit juices) and vegetable intakes (excluding french fry products) were recorded in daily servings based on food photos.; Age(s) at outcome assessment: 26.52 (8.48) mo [1-3 y] | Fruit intake (servings/day), Between group change score mean (SD); [underlined: Intervention vs.][underlined: Control:] 0.89 (1.93), p<0.001; Vegetable intake (servings/day), Between group change score mean (SD); [underlined: Intervention vs.] [underlined: Control:] 0.60 (1.64), p<0.001 | | Key confounders accounted for: parental BMI; Key confounders NOT accounted for: SEP and/or parental education, race and/or ethnicity, child’s intake at baseline, child’s anthropometry at baseline, child’s sex; Model adjustments: Location of recruitment, parental BMI; Funding: The Graduate School and Department of Nutritional Sciences at Texas Tech University (partial funding)
Tovar, 2023^18^; RCT-parallel, Families Start at; Home/Familias Fuertes Comienzan en Casa, U.S.; Intervention: 27%, control: 46% Power Analysis: Not powered to detect significant differences in component scores; Primary Aim: To determine the feasibility of the study protocols, recruitment, the acceptability and fidelity of the intervention and its preliminary efficacy on changes in children’s diet quality and food parenting practices compared to an attention control group.; Caregiver Characteristics; - Mother: 90.5%, Father or other: 9.5%; - Age: 34.48 (7.59) y; - Race/Ethnicity: White: 38.1%, Hispanic/ Latinx: 87.3%, Multiracial: 17.5%, Unknown: 23.8%, Other: 20.6%; - Education: <8th grade: 14.3%, High school: 36.5%, College: 49.2%; - SEP, Other: Employment status: Full time: 23.8%, Part time: 20.6%, Other: 55.6%; Annual household income: <$25,000: 54%, $25,000–74,999: 31.7%, >$75,000:4.8%, Unknown: 9.5%; Food assistance (SNAP, WIC< Free or Reduced-Price Meals): 81%; Child Characteristics; - Female: 44%; - Baseline Intake: HEI total score: 61.06 Total fruits component: 3.88; Whole fruits component: 3.42; Total vegetables component: 1.77; Whole grains component: 3.89 | Int: Intervention, n=33: 3 monthly home visits (60–75 min) followed by 3 monthly phone calls (30–45 min). The community health worker (CHW) and parent developed a food parenting and nutrition plan based on motivational interviewing. The specific goal(s) focused on food parenting practices (‘how parents interact with children around meals’), and the home food environment, reasons for the plan, potential barriers to completing the plan and some possible solutions (including social supports). A handout with nutrition and food parenting guidance on creating family routines around healthy eating, empowering children to make healthy choices, choosing and preparing healthy family meals and snacks on a budget, meal planning and tips on how to involve children in family meal planning and preparation were handed at each visit. A tailored handout based on child’s appetitive traits using the Child Eating Behavior Questionnaire (at baseline) were also provided.; Control: Control, n=30: Parents received an attentionmatched intervention about school readiness promotion adapted from R.E.A.D.Y. (Read Educate and Develop Youth). Parents received the same intervention components as the intervention group, pertinent to school readiness instead of nutrition and included video assessment of a parent reading or completing an activity with their child, and 3-monthly phone calls to check in on progress related to their goals, text messages and printed materials.; Child age at start of intervention: 2-5 y; Intervention Duration: 6 mo; Compliance: Adherence: 88% Participant engagement (0=10): 9.7 Read between-visit text messages: 95 % Read mailed handouts: 73 %; Outcome(s): HEI-2015, fruit, vegetable, whole grains; Outcome assessment method: Parents completed two 24-h dietary recalls (multiple-pass approach). The data was collected and analyzed using NDSR software. HEI- 2015 total and component scores were derived using the National Cancer Institute simple HEI scoring algorithm method.; Age(s) at outcome assessment: 2-5 y | HEI-2015 total fruits component score, Effect size (Cohen’s δ) (95% CI); [underlined: Intervention vs][underlined: control:] 0.82 (0.16, 1.47), p<0.05; HEI-2015 whole fruits component score, Effect size (Cohen’s δ) (95% CI); [underlined: Intervention vs] [underlined: control:] 0.83 (0.17, 1.48), p<0.05 | HEI-2015 total score, Effect size (Cohen’s δ) (95% CI); Intervention vs control: −0.04 (−0.67-0.59), p≥0.05; HEI-2015 total vegetables component score, Effect size (Cohen’s δ) (95% CI); [underlined: Intervention vs][underlined: control:] −0.23 (0.86, 0.41), p≥0.05; HEI-2015 whole grains component score, Effect size (Cohen’s δ) (95% CI); [underlined: Intervention vs] [underlined: control:] 0.02 (0.61, 0.65), p≥0.05 | Key confounders accounted for: SEP and/or parental education, race and/or ethnicity, child’s anthropometry at baseline, child’s sex, child’s intake at baseline; Key confounders NOT accounted for: parental BMI; Model adjustments: Parental age, marital status, income, race/ethnicity, birth country, years in the USA, household composition, household chaos, child age, gender, BMI, and childcare attendance, baseline values of the corresponding outcome; Funding: National Heart, Lung, and Blood Institute

a Abbreviations: CFP: Caregiver feeding practice; CFQ: Caregiver Feeding Questionnaire; HEI: Healthy Eating Index; FFQ: Food Frequency Questionnaire; NDSR: Nutrition Data System for Research; NR: Not Reported; PCS: Prospective cohort study; RCT: Randomized Control Trial; SEP: Socioeconomic position

b Food parenting practices that fall within this bucket are underlined.

c Ogden J, Reynolds R, Smith A. Expanding the concept of parental control: a role for overt and covert control in children’s snacking behaviour?. Appetite. 2006;47(1):100–106. doi:10.1016/j.appet.2006.03.330 16682098

Table 17 Risk of bias for observational studies examining the relationship between autonomy supportive feeding practices during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Metcalfe, 2018^24^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Wilson, 2019^10^ | SOME CONCERNS | HIGH | LOW | HIGH | LOW | SOME CONCERNS | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 18 Risk of bias for randomized controlled trials (parallel) examining the relationship between autonomy supportive feeding practices during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans^a^

Article | Randomization | Deviations from the intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of reported result | Overall
Lee, 2023^13^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Tovar, 2023^18^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 19 Evidence examining the relationship between parental and caregiver feeding styles during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans?^a^,^b^

Study and Population Characteristics | Intervention/Exposure and Comparator, Outcome | Significant Results | Non-Significant Results | Confounders, Model Adjustments, Funding
Kamdar, 2019; PCS, U.S.; Analytic N=126; Power Analysis: NR; Primary Aim: To investigate if food insecurity affects child body mass index (BMI) through parental feeding demandingness and/or responsiveness and dietary quality 18 months later among low-income Hispanic preschoolers.; Caregiver Characteristics; - Mothers: 98.4%, Grandmothers: 1.6%; - Age: NR; - Race/Ethnicity: Hispanic: 100%; - Education: Some high school or less: 38.7%, High school/GED: 24.1%, Technical school/ Some college: 32.1%, College graduate: 5.1%; - SEP, Other: Employed: 23.4%, Unemployed: 76.6%; Child Characteristics; - Female: 48%; - Baseline Intake: HEI-2015 @ 4 y: 60.51 (9.47) | Exposure and Comparator:; Demandingness: control by parents with respect to their child’s feeding/eating Responsiveness: promotion of child autonomy (e.g., reasoning, complimenting, and helping the child to eat) (Continuous); Child age at initial exposure measurement: 4.8 y; CFS Assessment Method: Caregiver’s Feeding Styles Questionnaire (CFSQ); Reporting Method: Caregiver selfreported; Outcome(s): HEI-2015; Outcome assessment method:; Parents completed 3 24-h recalls (first in-person, 2 via phone) and teachers provided information about meals consumed at Head Start. Data was entered into NDSR and used to calculated HEI-2015 scores.; Age(s) at outcome assessment: 6.3 y | | HEI-2015 @ ~ 6y, B (SE); [underlined: Demandingness:] −0.50 (2.0), NS; HEI-2015 @ ~ 6y, B (SE); [underlined: Responsiveness:] 7.54 (7.57), NS | Key confounders accounted for: SEP and/or parental education, race and/or ethnicity, child’s anthropometry at baseline, child’s sex, parental BMI; Key confounders NOT accounted for: child’s intake at baseline; Model adjustments: Child gender, number of household members and children, parental Hispanic and English acculturation, marital status, parental employment status, parental education level, parental BMI, child BMI at baseline. Cross-lagged model also included food insecurity; Funding: National Institute of Child Health and Human Development; the Robert Wood Johnson Future of Nursing Scholars Program.
Ip, 2018; PCS, the Niños Sanos study, U.S.; Analytic N=237; Power Analysis: NR; Primary Aim: To identify and describe feeding styles used by mothers in farmworker families with 2.5- to 3.5-year-old children, describe how styles change over time, and characterize the relationship of feeding styles to dietary outcomes and measures of overweight and obesity; Caregiver Characteristics; - Mothers: 100%; - Age: 18 to 25y: 29%, 26 to 35y: 55.7%, 36 to 45y:15.3%; - Race/Ethnicity: Latino: 100%; - Education: 0 to 6 y: 43.6%, 7 to 9 y: 30.7%, 10+y: 25.8%; - SEP, Other: Farmworkers: 100%; - Migrant: 27.4%, Seasonal: 72.6%; Child Characteristics; - Female: 52%; - Baseline Intake: Whole grains (0-5): 2.7, Fruits (0-10): 4.49, Vegetables (0-10): 3.42 | Exposure and Comparator:; State 1 (low Parent-Centered (PC)/moderate Child-Centered (CC)): low use of PC strategies and contingency management, and moderate use of CC techniques, State 2 (high PC/high CC without physical control): high use of PC strategies and contingency management and high use of CC strategies, State 3 (high PC/high CC) use of all forms of PC control, including physical force, as well as high levels of CC feeding, State 4 (moderate PC/moderate CC; balanced approach) use of low to moderate levels of PC control and moderate levels of CC control, higher than state 1, but lower than states 2 and 3. (Categorical); Child age at initial exposure measurement: 2.5-3.5 y; CFS Assessment Method: Caregiver’s Feeding Style Questionnaire (CFSQ); Reporting Method: Caregiver self-reported; Outcome(s): Fruits, Vegetables, Whole grains; Outcome assessment method: Mothers/caregivers completed 3 24-h recalls (diet data for children enrolled in preschool collected directly from caregivers). Data was used to calculate Revised Children’s Dietary Quality Index (RC-DQI). Only a composite score and select components (sugar, fat whole grains, fruit, vegetables and dairy) was used in the analysis.; Age(s) at outcome assessment: 3.5- 4.5y; 4.5-5.5y | Vegetable Intake 3.5-5.5 y, Mean (95%CI); [underlined: State 3 vs. State 1 (ref):] 4.03 vs. 3.18 (0.3 to 1.4), p<0.01; Whole grains Intake 3.5-5.5 y, Mean (95%CI); [underlined: State 3 vs. State 1 (ref):] 3.10 vs. 2.57 (0.2 to 0.9), p<0.01; [underlined: State 4 vs. State 1 (ref):] 2.86 vs. 2.57 (0.01 to 0.7), p<0.05 | Fruit Intake 3.5-5.5 y, Mean (95%CI); [underlined: State 2 vs. State 1 (ref):] 4.45 vs. 4.32 (−0.3 to 0.8), p≥0.05; [underlined: State 3 vs. State 1 (ref):] 4.63 vs. 4.32 (−0.2 to 4.0), p≥0.05; [underlined: State 4 vs. State 1 (ref):] 4.81 vs. 4.32 (−0.1 to 1.0), p≥0.05; Vegetable Intake 3.5-5.5 y, Mean (95%CI); [underlined: State 2 vs. State 1 (ref):] 3.55 vs. 3.18 (−0.2 to 0.9), p≥0.05; [underlined: State 4 vs. State 1 (ref):] 3.37 vs. 3.18 (−0.4 to 0.7), p≥0.05; Whole grains Intake 3.5-5.5 y, Mean (95%CI); [underlined: State 2 vs. State 1 (ref):] 2.55 vs. 2.57 (−0.2 to 0.5), p≥0.05 | Key confounders accounted for: SEP and/or parental education, race and/or ethnicity, child’s sex; Key confounders NOT accounted for: child’s intake at baseline, child’s anthropometry at baseline, parental BMI; Model adjustments: Child sex, child age at baseline, migrant status.; Funding: NICHHD; NHLBI; the National Center for Advancing Translational Sciences, NIDDKD, the National Science Foundation.

a Abbreviations: CFS: Caregiver feeding styles; HEI: Healthy Eating Index; NR: Not Reported; PCS; Prospective cohort study; SEP: Socioeconomic position

b Feeding styles that fall within this bucket are underlined.

Table 20 Risk of bias for observational studies examining the relationship between caregiver feeding styles during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Kamdar, 2019^26^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Ip, 2018^25^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.