# Results

## Literature search and screening results

The literature search (Appendix 2) yielded 9230 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 5852 titles, 2412 abstracts, and 940 full-texts articles. Reasons for full-text exclusion are in Appendix 3. No additional articles were identified from the manual search. The body of evidence included 26 articles.

Figure 2 Literature search and screen flowchart

The literature search in PubMed, Embase, Cochrane, and CINAHL, retrieved 9,230 records after removing duplicates. None were found with manual search methods. 5,852 titles, 2,412 abstracts, and 940 full-texts were excluded. 26 articles were included in the systematic review.

Fourteen articles from prospective cohort studies (PCS) and 12 articles (9 cohorts) from randomized control trials (RCT) met inclusion criteria and examined the associations between parental and caregiver feeding styles and practices and dietary patterns aligned with the Dietary Guideline for Americans.

## Structured feeding practices

### Description of the evidence

A total of 22 articles met inclusion criteria and examined the associations between caregiver feeding practices related to structuring child’s physical and social environment and dietary intakes aligned with the Dietary Guidelines for Americans (Table 9): 10 prospective cohort studies (PCS)^1–10^ and 12 randomized controlled trials (RCT).^11–22^

#### Population

Most studies were conducted in the U.S.^1,2,7,8,10–13,15–18^; however, there were also studies from Australia,^5,19–22^ Netherlands,^6,9^ the United Kingdom,^3,14^ and Finland.^4^

Ten of the 22 articles were PCS; 5 articles were a secondary analysis of data from a RCT.^1,4,7,9,10^ Sample sizes ranged from N=51^7^ to N=7285^3^ participants with 5 articles involving sample sizes less than 1000 participants.^1,4,5,7,10^ Five articles reported that a majority of children in the sample were with overweight or obesity at baseline^1,2,4,7,10^ and 1 article reported data from participants enrolled in an overweight prevention protocol.^9^

Three of the 10 PCS did not report race and/or ethnicity data^3–5^ and 1 article did not report information on SEP.^7^ Of those that did provide information on race and/or ethnicity, 3 articles were studies in predominantly white populations ^2,7,8^ 2 articles reported that >50% of participants were from racial and/or ethnic minority groups,^1,10^ and 2 articles reported that most participants were Dutch.^6,9^ Seven articles were from studies conducted in middle to higher SEP populations^2–6,8,9^ while 2 articles were from studies conducted in lower SEP populations.^1,10^

The 12 articles from RCT were from 9 independent trials; 4 articles reported findings from the Healthy Habits trial.^19–22^ Sample sizes ranged from N=39^15^ to N=1306.^11^ Eleven of the articles reported a power analysis,^11,12,14–22^ however only 2 studies were adequately powered to detect differences in dietary outcomes.^11,14^

Of the 12 RCTs, 5 trials were conducted in predominantly white populations^11,12,14,16,17^ and 3 trials reported that >50% of participants were from underrepresented racial and/or ethnic groups.^13,15,18^ The Healthy Habits trial included 5% participants who were Aboriginal and/or Torres Strait Islander.^19–22^ All 12 articles from RCTs articles reported information on participants’ SEP; 3 articles were from studies conducted in middle to higher SEP populations^12,16,17^ and 9 articles were from studies conducted in lower SEP populations.^11,13–15,18–22^ Five articles reported baseline anthropometry of children in the sample; 5 studies reported >50% were normal weight (Body Mass Index (BMI) <85^th^ percentile or z-score between −1 and 1) at baseline.^12,13,15–17^

#### Intervention/Exposure

Structure involves caregivers’ organization of children’s environment to facilitate children’s competence.^*^ Structured feeding practices encompass caregivers’ consistent enforcement of rules and boundaries about eating, strategies used by caregivers to help their children learn and maintain certain dietary behaviors, and the caregivers’ physical organization of their children’s food environment. These practices may include rules, limits or boundaries, limited/guided choices, portion size, monitoring, meal- and snack time routines (atmosphere of meals, distractions [e.g., screens], family presence, and meal and snack schedule), modeling, food availability and accessibility, and food preparation, and unstructured (indulgent feeding practices).

* Vaughn AE, Ward DS, Fisher JO, . Fundamental constructs in food parenting practices: a content map to guide future research. Nutr Rev. 2016 Feb;74(2):98–117.26724487

All PCS articles examined varying levels of caregiver feeding practices as their exposure and comparator of interest. Feeding practices were assessed using caregiver self-report when children were between 2 and 6 years; 8 articles reported the average age of children was >4 years,^1,3,4,6–10^ 1 article reported the average age of children was 24 months,^2^ and 1 article reported children were between 6 months and 6 years.^5^ Three articles assessed availability of foods,^4,7,9^ 4 articles assessed frequency and/or environment of family meals,^2,5,6,8^ 4 articles assessed monitoring of children’s eating,^1,6,9,10^ 2 articles assessed modelling,^4,10^ and 4 articles assessed having rules related to eating.^3,4,7,9^

The RCTs were comprised of a variety of intervention components, but most included materials and activities aimed at increasing the availability of fruits and vegetables in the home and/or positively structuring family mealtimes.^11–22^ The control groups received information unrelated to the intervention^11,13,14,16–22^ or were waitlisted to receive the intervention after the study period.^12,15^ The duration of the trials ranged from 4 weeks^19–22^ to 8 months.^16^ More information on interventions and comparators is provided in Table 9.

#### Outcome

For the PCS, outcomes were assessed when children were approximately 4 years^2,7^, 5 years^2,4,6,7,9,14–16^, 6 years^6,18^, 7 years,^1,10,18^ 8 years,^4,6,8–12,14,17,19–22^ and 13 years.^8^ One study measured outcomes 2 years after baseline when children were between 1.5 years and 8 years.^5^ Outcomes included measures of dietary quality, including Healthy Eating Index (HEI) scores or intakes of fruits, vegetables, whole grains or SSBs. The most commonly reported outcomes were intakes of fruits and vegetables (17 articles)^3–6,8,11–22^ and SSBs (8 articles).^2,4,6,7,9,14–16^ Only 2 articles reported on intakes of whole grains^6,18^ and 3 articles reported on overall diet quality using HEI scores.^1,10,18^ Thirteen studies assessed diet using a food frequency questionnaire,^4,6,8–12,14,17,19–22^ 4 studies used 24- hour recalls^1,7,16,18^ and 5 studies used other methods.^2,3,5,13,15^

### Synthesis of the evidence

#### Prospective Cohort Studies

Five PCS showed positive associations between structured feeding practices with fruit and vegetable intakes among children.^3–6,8^ Three articles reported higher frequency of family meals was related to greater intakes of fruit and vegetables,^5,6,8^ though not all of the associations reached significance.^5,8^ Three PCS assessed monitoring, availability of healthy foods, and/or having rules regarding eating healthy foods and showed positive associations with fruit and vegetable intake.^3,4,6^

Five studies included outcomes related to SSB consumption and showed inconsistent findings.^2,4,6,7,9^ One study found higher frequency of having breakfast, but not dinner, with fathers was associated with a decrease in the odds of children drinking SSB beverages at 2-year follow-up.^2^ In a different study, frequency of family breakfast and dinner, as well as parental monitoring, were not associated with SSB intake.^6^ Two PCS assessed rules (limit setting): 1 study found a positive association between having rules and low SSB intake over time,^9^ and 1 study found no association with SSB intake.^7^ van Grieken et al.^9^ also found that greater monitoring of child’s SSB consumption, not buying SSB, and no availability of SSB in the home were associated with low SSB intake over time. One other study reported that decreased availability of SSB was related to decreased SSB intake.^4^

Measures of whole grain intake and overall diet quality using HEI scores were each reported in 1 PCS.^1,6^ Mou et al.^6^ reported that monitoring and higher frequency of family breakfast and dinner were associated with higher whole grain component scores among children. Buscemi et al.^1^ examined overall diet quality and found no association between parental monitoring and changes in HEI scores from baseline to follow-up.

#### Randomized Control Trials

Twelve RCTs that included structured feeding practices as an intervention component demonstrated positive effects on children’s dietary patterns, particularly fruit and vegetable intake.^11–22^ Children randomized to the intervention group of the Healthy Habits trial had an increase in mean intake of fruit and vegetables compared to the control group at 2-month and 6-month follow-up^22^ as well as 12-month follow-up, but not the 18-month follow-up.^19,21^ At the 5-year follow-up, there were no differences in child consumption of fruit but there was a higher consumption of vegetables by children randomized to the intervention group.^20^ Another unnamed trial focused on parent behaviors to increase consumption of fruits and vegetables also showed an increase in the vegetable intake among children randomized to the intervention group, but no change in fruit intake.^12^ Two other trials, the Poppets Healthy Feeding Habits Intervention^14^ and another unnamed trial^13^ also showed a significant increase in daily intake of fruit and vegetables among children randomized to the intervention that focused on increasing availability and accessibility of fruits and vegetables. The Strong Families Start at Home trial showed a positive effect of the intervention on whole and total fruit component scores but not vegetable component scores.^18^ Another study reported that improving the family mealtime environment improved the frequency of vegetable intake in children.^15^ The High 5 for Kids trial had differential effects of the intervention on fruit and vegetable intake depending on child weight status at baseline. Fruit and vegetable intake increased among children categorized as normal weight but not those categorized as overweight relative to controls.^11^ The Family Ties to Health trial focused on availability of vegetables and role modeling of eating vegetables.^17^ In this study, there were no differences in vegetable intake between children randomized to the intervention group or the control group after the intervention.^17^ The KAN-DO (Kids and Adults Now — Defeat Obesity!) trial also showed no difference in fruit and vegetable intake between intervention and control group.^16^

Few of these interventions examined other dimensions of dietary patterns. One study assessed overall diet quality using the Healthy Eating Index as well as intakes of whole grain^18^ and 2 studies assessed SSB consumption and mostly showed null results.^14,15^ Only children randomized to the Poppets Healthy Feeding Habits Intervention showed a within-group decrease in SSB consumption post-intervention.^14^

Studies had numerous risk of bias concerns across domains (Table 10, Table 11, Table 12). For prospective cohort studies, risk of bias concerns were related to not accounting for key confounders, self-reported exposures and outcomes, post-exposure interventions that could influence the relationship between exposures and outcomes, and lack of pre-registered analysis plan. For the randomized controlled trials, risk of bias concerns were related to lack of specificity on outcome measurement and missing pre-analysis plan.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed and graded a conclusion statement to answer the question, “What is the relationship between parental and caregiver feeding styles and practices during childhood and consuming a dietary pattern aligned with the Dietary Guidelines for Americans?” based on their review of the body of evidence on structured feeding practices by caregivers of children ages 2 to 6 years (Table 5). The grade reflects the strength of the evidence underlying the conclusion statement.

Table 5 Conclusion statement, grades for structured feeding practices and consuming a dietary pattern aligned with the Dietary Guidelines for Americans

Conclusion Statement | Food parenting practices by caregivers of children ages 2 to 6 years that structure children’s physical and social eating environments (e.g. availability and accessibility of healthy foods, monitoring children’s eating, modeling of healthy eating behaviors, meal routines such as eating together as a family) are associated with higher intake of fruits and vegetables. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 22 articles: 10 PCS; 12 RCT
Consistency | Minimal concerns with consistency
Precision | Minimal concerns with precision
Risk of bias | Some concerns with risk of bias particularly due to confounding, exposure and outcome measurement
Directness | Minimal concerns with directness
Generalizability | Some concerns with generalizability due to lack of representation from diverse samples from the U.S. and few studies that assessed feeding practices from caregivers other than mothers.

#### Assessment of the evidence

The body of evidence examining structured feeding practices and consuming a dietary pattern aligned with the Dietary Guidelines for Americans includes 22 articles from 10 PCS and 12 RCT. The evidence was graded based on an assessment of 5 grading elements, as described below. Publication bias was also a consideration; however this was not assessed as a serious concern because the body of evidence included studies that reported only nonsignificant findings as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

##### Consistency

There were few concerns with consistency in the body of evidence. Food parenting practices by caregivers that positively structure children’s physical and social eating environments, which included availability and accessibility of healthy foods, monitoring, modeling of healthy eating behaviors, meal routines such as eating together as a family, were associated with higher intake of fruits and vegetables.

##### Precision

There were minimal concerns with precision.

##### Risk of bias

Risk of bias assessments for each article are detailed in Table 10, Table 11 and Table 12. There were serious concerns with numerous risks of bias domains, which may potentially influence the results that were reported in the articles. There were concerns with confounding since many articles from observational studies did not account for 1 or more key confounders. Across the body of evidence, the assessment of caregiver feeding practices was a potential concern due to the reliance on self-report and use of non-validated measures. Outcome measurement was also a concern for articles that used a non-validated measures and those that assessed frequency of intake rather than the actual amount of dietary intake. Many articles failed to provide evidence that their results were not biased by missing data. Lastly, the selection of reported results was a concern for articles that did not pre-register data analysis plans.

##### Directness

Most articles directly examined the relationship between structured feeding practices and fruit and vegetable intakes among children. The randomized controlled trials included some components other than caregiver feeding practices, but these components were closely related to parent-child feeding interactions and the interventions’ primary aims were related to the healthy home food environment.

##### Generalizability

There were some concerns with generalizing the findings to the U.S. populations. Although more than half of the studies (12 articles) were from the U.S., the majority of participants in these studies were white. Only a few articles included participants with diverse race and ethnic backgrounds. Additionally, few studies reported on feeding practices from caregivers other than children’s mothers.

## Controlling feeding practices

### Description of the evidence

Six studies met inclusion criteria and examined the associations between controlling caregiver feeding practices in children ages 2 to 6 years and dietary outcomes Table 13.^1,6,9–11,23^ Five studies were prospective cohort design or secondary analysis of RCTs, using data from the following cohorts/trials: Generation R,^6^ Be active, eat right,^9^ HH Effectiveness,^1^ Project Viva,^23^ and MEND2-5/MEND/CATCH6-12/Next Steps.^10^ One study was a cluster randomized controlled trial using data from High 5 for Kids.^11^

#### Population

The studies took place in the U.S.^1,10,11,23^ and Netherlands.^6,9^ The analytic sample sizes ranged from N=147^10^ to N=3626^6^ participants. None of the PCS reported power calculations related to controlling feeding practices. The randomized controlled trial was powered to detect differences in dietary outcomes.^11^

Caregivers were reported as 100% parents,^1^ 86-100% mothers,^6,11,23^ 90.6% female,^9^ and 100% caregivers.^10^ Information on racial and/or ethnic background of participants was provided in all 6 studies^1,6,9–11,23^ In the studies from the U.S., samples were predominantly white,^11,23^ black^1^ or Hispanic.^10^ In the 2 studies from the Netherlands, participants were Dutch ethnicity.^6,9^ SEP, including education, was described in all 6 studies: 3 studies reported a majority of participants from higher SEP based on education^6,9,23^ and 3 studies reported participants were from lower SEP based on education or income level.^1,10,11^

Regarding the children in these 6 samples, approximately 50% of participants were female.^1,6,9–11,23^ Baseline BMI were reported in each of the prospective studies: one study reported BMI SD score of 0.1,^6^ 1 study reported BMI of 15.4,^9^ 1 study reported BMI z-score of 0.64,^1^ 1 study reported BMI z-score 0.71,^23^ and the last study reported a comparison of BMI percentile between the treatment group (96.8) and comparison group (97.0) from the trial.^10^ Children’s baseline dietary intake was reported in 5 of 6 studies: 1 study reported that children consumed 3 servings per day of sugar sweetened beverages at baseline,^9^ 1 study reported that children consumed approximately 3.3 servings of fruit per day and 1.5 servings of vegetables per day,^11^ 2 studies reported baseline HEI scores as 55.4^23^ and 59.97,^10^ and 1 study reported a baseline estimate of diet quality as −0.762.^1^

#### Intervention/ exposure

For the 5 PCS, caregiver feeding practices were measured at a single timepoint when children were on average 2 years,^23^ 4 years,^6,10^ or 5 years of age.^9^ One study assessed changes in feeding practices from 3 to 6 years.^1^ Of the controlling feeding practices that were assessed, 3 studies assessed restriction,^1,6,23^ 3 studies assessed pressure to eat,^1,6,23^ 1 study assessed overt control,^10^ and 1 study assessed discouraging and not allowing the child to consume sugar-sweetened beverages.^9^ All feeding practices were assessed using self-report questionnaires.

For the trial, families with preschool-aged children between 2 and 5 years were randomized to an intervention or control group by Parent as Teachers (PAT) program site.^10^ PAT is a nationwide program that emphasizes empowering parents as their child’s teacher and encourages positive parent-child communication via home visits, on-site group activities, and newsletters. The intervention group received PAT curriculum as well as the High 5 for Kids (H5-Kids) curriculum. The H5-Kids curriculum consisted of tailored information for increasing fruit and vegetable intake disseminated via newsletters and home visits. Key program areas included knowledge, parental modeling of fruit and vegetable intake, noncoercive feeding practices and fruit and vegetable availability. Participants randomized to the control received only the PAT curriculum.^10^ The trial duration was approximately 7 months.

#### Outcome

For the PCS, outcomes were assessed when children were on average 3 years,^23^ 5 years,^1,10^ 7 years,^9^ and 8 years.^6^ The RCT assessed outcomes at the end of the intervention^11^ Fruit and vegetable intake was measured in 3 studies: 1 study used a fruit and vegetable component score^6^ and 2 studies measured fruit and vegetable servings per day.^11,23^ Whole grain intake was measured in 1 study using a whole grain component score.^6^ Sugar sweetened beverage intake was measured in 3 studies: 1 study used a sugar containing beverage component score,^6^ study measured sugar sweetened beverage and fruit juice servings per day,^23^ and 1 study measured sugar sweetened beverage intake as glasses per day and determined high and low consumption.^9^ Three studies measured overall diet quality scores using the HEI^1,10^ or Youth Healthy Eating Index.^23^ Dietary outcomes were most commonly assessed using food frequency questionnaires^6,9–11,23^ and 1 study used a 24-hour recall in combination with meal observations.^1^

### Synthesis of the evidence

Across the 6 studies, associations between controlling feeding practices with dietary outcomes varied in direction and magnitude of the effect.^1,6,9–11,23^

Among the 3 studies that assessed fruit and vegetable outcomes,^1^ study reported negative associations between pressure to eat and fruit and vegetable intake, and positive associations between restriction and fruit component intake, but negative associations between restriction and vegetable intake.^6^ One study reported positive associations between restrictive feeding and servings per day of fruits and vegetables, but negative associations between pressure to eat and servings per day of fruits and vegetables.^23^ In both studies, not all associations reached statistical significance. The randomized trial assessed effects of the H5-Kids intervention on fruit and vegetable intakes and reported increased fruit and vegetable intakes as a result of the intervention among normal weight children only, but no association between changes in noncoercive feeding practices and change in children’s fruit and vegetable intakes.^11^

Among the 3 studies that assessed dietary quality outcomes, one reported positive associations between pressure to eat and youth HEI scores at age 3 but not 7 years, and 2 studies reported null associations between pressure to eat,^1^ restriction,^1^ and control^10^ with HEI scores.

Two studies reported significant associations between controlling feeding and intakes of sugar sweetened beverages, but direction of the effect were inconsistent between studies.^9,23^ One study reported negative associations between discouraging and not allowing intakes of sugar sweetened beverages with consumption of sugar sweetened beverages.^9^ The other study reported positive associations between restriction at age 2 and intake of sugar sweetened beverages and fruit juice at age 3, but null associations at age 7.^23^ A third study reported negative associations between pressure to eat and restriction with sugar containing beverages component scores that did not reach statistical significance.^6^

Studies had numerous risk of bias concerns across domains including: not accounting for key confounders, use of self-reported measures for exposures and outcomes, post-exposure interventions that could influence the relationship between exposures and outcomes, and lack of a pre-registered analysis plan (Table 14, Table 15). Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence predominantly included studies that reported only nonsignificant findings, as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between parental and caregiver feeding styles and practices during childhood and consuming a dietary pattern aligned with the Dietary Guidelines for Americans?” based on their review of the body of evidence on controlling feeding practices by caregivers of children ages 2 to 6 years (Table 6). A conclusion statement could not be drawn due to substantial concerns with consistency in the body of evidence.

Table 6 Conclusion statement, grades for controlling feeding practices and consuming a dietary pattern aligned with the Dietary Guidelines for Americans

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between controlling food parenting practices (e.g. pressure to eat, overt limits on consumption of certain foods) by caregivers of children ages 2 to 6 years and outcomes related to consuming a dietary pattern aligned with the Dietary Guidelines for Americans because there are substantial concerns with consistency in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 6 studies: 5 PCS; 1 RCT
Rationale | The evidence available to answer this question was inconsistent in the direction and magnitude of effect making it difficult to synthesize together.

## Autonomy supportive feeding practices

### Description of the evidence

Four articles met inclusion criteria and assessed associations between food parenting practices that provide developmentally appropriate support for children’s autonomy and dietary outcomes (Table 16).^10,13,18,24^ Two articles were PCS^10,24^ and 2 articles were from RCTs.^13,18^

#### Population

All 4 studies were conducted in the U.S.^10,13,18,24^ The analytic sample size ranged from 63 participants^18^ to 497 participants.^24^ Only 1 study reported a power analysis and was not powered to detect significant differences in dietary outcomes.^18^

Of the 2 PCS included in the body of evidence, 1 study was conducted in a sample of low-income caregivers enrolled in the MEND/MEND 2-5 trials and CATCH 6-12.^10^ In this study, 86% of caregivers were Hispanic and 12% were non-Hispanic black; 44% had less than high school education and 80% had an annual household income of less than $25,000. The mean maternal BMI was approximately 33.2. Approximately 50% of children in the sample were female and at baseline, the average HEI score was 59.87.^24^ The second study included caregivers who were enrolled in STRONG Kids 1 and described as 100% parents.^24^ In this sample, 55.9% of caregivers were white, 26.4% were black, 6.8% were Hispanic, 9.7% were Asian, and 1.2% were American Indian and Native Hawaiian. In terms of socioeconomic status, approximately 31% of participants had a household income of less than $25,000, 14.7% made between $25,000 and $39,999, 18.9% made between $40,000 and $69,999, 16.9% made between $70,000 and $99,999 and 18.5% had a household income of greater than $100,000. Caregivers’ BMI or weight status was not reported. Approximately 50% of children in the sample were female and dietary intakes at baseline were not reported.

One RCT included participants enrolled in an unnamed randomized controlled trial.^13^ This sample included 84.9% mothers, 8.2% fathers, 5.5% foster mothers, and 1.4% grandmothers. In terms of socioeconomic status, 42.4% had a high school degree or less, 50.6% had some college or a college degree, and 6.8% had a Master’s degree and the average yearly income was $26,436.97. 46.6% of caregivers were with obesity, 34.2% were with overweight, and 19.2% were in the healthy weight range. In this study, 21.9% of children were white, 16.4% were black, 23.3% were Hispanic, 36.9% were described as biracial, and 1.4% were Native Hawaiian and other Pacific Islander.^13^ Approximately 56% of children in the sample were female. At baseline, the control group consumed approximately 0.47 servings of fruit per day and 0.44 servings of vegetables, and the intervention group consumed approximately 0.57 servings of fruit per day and 0.45 servings of vegetables.^13^

The other RCT included participants enrolled in the pilot study, Families Start at Home/ Familias Fuertes Comienzan en Casa.^18^ This sample included 90.5% mothers and 9.5% fathers from low-income families. The sample was predominantly Hispanic/LatinX: 87% were Hispanic/LatinX, 38.1% white, 17.5% multiracial, 23.8% unknown race and ethnicity and 20.6% other race.^18^ The average age of caregivers in this sample was approximately 34 years, 14.3% had less than 8^th^ grade education, 36.5% had high school education, and 49.2% had a college education. In terms of household income, 54% had an annual income of less than $25,000, 31.7% had between $25,000-$74,999, 4.8% had greater than $75,000 and 9.5% were unknown. Approximately 44% of children in the sample were female. The children’s baseline HEI score was approximately 61, the total fruits component score was 3.88, the whole fruits component score was 3.42, the total vegetables component score was 1.77 and the whole grains component score was 3.89.^18^

#### Intervention/exposure

All studies measured caregiver feeding practices when children were between 2 and 4 years. One PCS assessed family food involvement when children were on average 3 years of age using a self-report questionnaire.^24^ The other PCS measured the use of reinforcement or praise when children were approximately 4 years of age using a self-report questionnaire.^10^

One RCT compared dietary intakes between children enrolled in a randomized controlled trial.^13^ As part of the trial, parents with children ages 1 to 3 years were randomized to an e-health intervention group or a control group. The 8-week e-health intervention involved researcher-developed videos on nutrition and responsive feeding practices, cooking tutorials and reminders with key messages from the videos. The control group received a booklet about general nutrition. Responsive feeding practices were assessed in both groups at baseline and post-intervention using a self-report questionnaire.

The other RCT compared dietary intakes between children enrolled in the 6- month randomized controlled trial, the Families Start at Home/ Familias Fuertes Comienzan en Casa.^18^ Families randomized to the intervention received 3 monthly home visit and 3 monthly phone calls, as well as handouts on nutrition, food parenting guidance, and their child’s appetitive traits. The focus of the intervention was on food parenting practices, or how parents interact with their child around meals, and the home food environment. This included empowering children to make healthy choices and involving children in family meal planning. Families randomized to the control group received a matched intervention about school readiness promotion, adapted from Read, Educate, and Develop Youth.^18^

#### Outcome

Reported outcomes varied across the 4 studies. One study assessed intakes of fresh fruit and vegetables, fruit juice and non-diet soda.^24^ Two studies assessed overall diet quality.^10,18^ The third study assessed between group change in fruit and vegetable intake from pre- to post-intervention.^13^

Metcalfe and Fiese^24^ and Wilson et al.^10^ assessed children’s dietary intakes when children were between 4 and 5 years old using a validated food-frequency questionnaire. Tovar et al.^18^ assessed diet when children were between 2 and 5 years using 2 24-hour recalls. In Wilson et al.^10^ and Tovar et al.^18^ dietary data were entered into the Nutrition Data System for Research (NDSR) and used to calculate HEI scores. In Lee et al.^13^ caregivers captured digital food photos of their children’s 24-intakes of meals, snacks and beverages at baseline and following the 8-week intervention. Daily servings of fruits and vegetables were calculated based on photos at both timepoints and used to determine changes in servings per day.

### Synthesis of the evidence

Studies in this body of evidence included a variety of feeding practices that provide developmentally appropriate support for children’s autonomy and evaluated associations with different dietary outcomes. However, significant positive associations were reported in all 4 studies.^10,13,18,24^ In 1 study, family food involvement at age 3 years was positively associated with fruit and vegetable intake at 4 years. ^24^ In 1 study, use of reinforcement or praise at 4 years was associated with higher overall diet quality at 5 years.^10^ In the third study, children who participated in an e-health intervention that focused on responsive feeding and general nutrition had greater increases in daily servings of fruit and vegetables compared with a control group.^13^ In Tovar et al.^18^ children enrolled in the intervention group that targeted food parenting practices and home food environment had greater HEI component score for total fruits and whole fruits compared with children randomized to the control group. Two studies also reported null associations: family food involvement at age 3 years did not predict fruit juice or non-diet soda intake at 4 years,^24^ HEI total scores and component score for total vegetables and whole grains did not differ between children randomized to the food parenting practices and home food environment intervention and children randomized to the control group.^18^

Studies had numerous risk of bias concerns across domains (Table 17 and Table 18). For prospective cohort studies, risk of bias concerns were related to not accounting for key confounders, self-reported exposures and outcomes, post-exposure interventions that could influence the relationship between exposures and outcomes, and lack of pre-registered analysis plan. For the randomized controlled trials, risk of bias concerns were related to lack of specificity on outcome measurement. Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence predominantly included studies that reported only nonsignificant findings, as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between parental and caregiver feeding styles and practices during childhood and consuming a dietary pattern aligned with the Dietary Guidelines for Americans?” based on their review of the body of evidence on autonomy supportive feeding practices by caregivers of children ages 2 to 6 years (Table 7). A conclusion statement could not be drawn due to lack of evidence.

Table 7 Conclusion statement, grades for autonomy supportive feeding practices and consuming a dietary pattern aligned with the Dietary Guidelines for Americans

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between food parenting practices by caregivers of children ages 2 to 6 years that provide developmentally appropriate support for children’s autonomy (e.g., responsive feeding, praise, child involvement in food and eating activities) and outcomes related to consuming a dietary pattern aligned with the Dietary Guidelines for Americans because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 4 studies: 2 PCS; 2 RCT
Rationale | There was a small number of studies available to answer this question and findings were mixed. There were inconsistencies in the autonomy supportive practices assessed, making it difficult to compare results across studies.

## Feeding styles

### Description of the evidence

Two studies met inclusion criteria and assessed associations between caregiver feeding styles and dietary outcomes (Table 19).^25,26^ Both studies were prospective cohort studies.^25,26^

#### Population

Both studies were conducted in the U.S.^25,26^ One study had a sample size of 126 participants^26^ and the other study had a sample size of 237 participants.^25^ Neither study reported a power analysis.

Kamdar et al.^26^ was conducted among a low-income sample of Hispanic women who were participating in Head Start. Caregivers in the sample were 98.4% mothers and 1.6% grandmothers. 38.7% had some high school education or less, 24.1% had a high school degree or GED, 32.1% had attended technical school or some college, and 5.1% were college graduates. The average maternal BMI was around 31.9. Approximately 48% of the children in this sample were female and at baseline, 0.7% were considered underweight, 48.9% were normal weight, 21.2% were with overweight and 29.2% were with obesity. The average HEI score at baseline was approximately 60.5.

Ip et al.^25^ was conducted among Latino mothers enrolled in the Ninos Sanos study. Participants were 100% farmworkers; 27.4% were migrants and 72.6% were seasonal. 43.6% had between 0 and 6 years of education, 30.7% had between 7 and 9 years, and 25.8% had over 10 years of education. Approximately 52% of children in the sample were female and the average BMI-for-age percentile was 72.8. At baseline, the average whole grains score was 2.7 out of 5, the average fruit score was 4.5 out of 10, and the average vegetables score was 3.4 out of 10.

#### Intervention/exposure

Caregiver feeding styles were measured when children were between 2.5 and 3.5 years^25^ and approximately 4 years.^26^ Both studies assessed caregivers’ responsiveness and demandingness using self-reported measures.^25,26^ In Ip et al.^25^ caregivers were assigned into 1 of 4 feeding style states based on their responses to the questionnaire. The 4 states were determined using Hidden Markov Modeling. State 1 was characterized by low use of parent centered strategies and moderate use of child centered techniques. State 2 was characterized by high use of parent centered and high use of child centered strategies without physical control. State 3 was characterized by high use of parent centered, including physical control, and high use of child centered strategies. State 4 was characterized by low to moderate levels of parent centered strategies and moderate levels of child centered strategies.^25^ In Kamdar et al.^26^ caregiver feeding responsiveness and demandingness were operationalized as continuous variables.

#### Outcome

The measured outcomes differed between studies. Kamdar et al.^26^ assessed overall diet quality when children were approximately 6 years using HEI scores. Ip et al.^25^ assessed intakes of fruit, vegetables, and whole grains when children were between 3.5 and 5.5 years using a diet index. In both studies, dietary data were collected using multiple 24-hour recalls and analyzed using NDSR.^25,26^

### Synthesis of the evidence

Both studies that examined feeding styles by caregivers of children 2 to 6 years and dietary outcomes reported predominantly null associations. In Kamdar et al.^26^ caregivers’ levels of demandingness and responsiveness did not predict children’s HEI scores at 6 years. In Ip et al.^25^ there were no differences in children’s fruit intake according to caregiver’s feeding style categorization, but this study did report significant associations between feeding style states with vegetable and whole grain intake. Specifically, children of caregivers who had a feeding style categorized by high use of parent centered, including physical control, and high use of child centered strategies (State 3) and those with caregivers who had a feeding style characterized by low to moderate levels of parent centered strategies and moderate levels of child centered strategies (State 4) had higher intakes of whole grains compared with caregivers with other types of styles. This study also reported that children of parents who had a feeding style categorized by high use of parent centered, including physical control, and high use of child centered strategies (State 3) had higher vegetable intakes compared with those who had caregivers with a feeding style characterized by low use of parent centered strategies and moderate use of child centered strategies (State 1).^25^

Studies had numerous risk of bias concerns across domains (Table 20). The risk of bias concerns were related to not accounting for key confounders, self-reported exposures and lack of pre-registered analysis plan. Publication bias was also a consideration; however, this was not assessed as a serious concern because the body of evidence predominantly included studies that reported only nonsignificant findings, as well as studies that reported a mix of both significant and nonsignificant results, across a range of analytic sample sizes. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between parental and caregiver feeding styles and practices during childhood and consuming a dietary pattern aligned with the Dietary Guidelines for Americans?” based on their review of the body of evidence on feeding styles by caregivers of children ages 2 to 6 years (Table 8). A conclusion statement could not be drawn due to lack of evidence.

Table 8 Conclusion statement, grades for caregiver feeding styles and consuming a dietary pattern aligned with the Dietary Guidelines for Americans

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between feeding styles by caregivers of children ages 2 to 6 years and outcomes related to consuming a dietary pattern aligned with the Dietary Guidelines for Americans because there is not enough evidence available (Grade Not Assignable).
Grade | Grade Not Assignable
Body of Evidence | 2 articles: 2 PCS
Rationale | Only 2 studies met the inclusion criteria and examined caregiver feeding styles and dietary patterns in children