# Plain language summary

### What is the question?

The question is: What is the relationship between parental and caregiver feeding styles and practices during childhood and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans? The population of interest for this question includes children ages 2 to 6 years.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a new systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team.

### What is the answer to the question?

- Food parenting practices by caregivers of children ages 2 to 6 years that structure children’s physical and social eating environments (e.g. availability and accessibility of healthy foods, monitoring children’s eating, modeling of healthy eating behaviors, meal routines such as eating together as a family) are associated with higher intake of fruits and vegetables. This conclusion statement is based on evidence graded as moderate.
- A conclusion statement cannot be drawn about the relationship between controlling food parenting practices (e.g. pressure to eat, overt limits on consumption of certain foods) by caregivers of children ages 2 to 6 years and outcomes related to consuming a dietary pattern aligned with the Dietary Guidelines for Americans because there are substantial concerns with consistency in the body of evidence.
- A conclusion statement cannot be drawn about the relationship between food parenting practices by caregivers of children ages 2 to 6 years that provide developmentally appropriate support for children’s autonomy (e.g., responsive feeding, praise, child involvement in food and eating activities) and outcomes related to consuming a dietary pattern aligned with the Dietary Guidelines for Americans because there is not enough evidence available.
- A conclusion statement cannot be drawn about the relationship between feeding styles by caregivers of children ages 2 to 6 years and outcomes related to consuming a dietary pattern aligned with the Dietary Guidelines for Americans because there is not enough evidence available.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 2000 – January 2024.