# Acknowledgments

The Committee members were involved in: establishing all aspects of the protocol, which presented the plan for how they would examine the scientific evidence, including the inclusion and exclusion criteria; reviewing all studies that met the criteria they set; deliberating on the body of evidence for each question; and writing and grading the conclusion statements. The NESR team, with assistance from Federal Liaisons and Project Leadership, supported the Committee by facilitating, executing, and documenting the work necessary to ensure the reviews were completed in accordance with NESR methodology.

The Committee and NESR staff thank staff from the National Institutes of Health (NIH), for coordinating the peer review of this systematic review, and the peer reviewers for their time and expertise.

The Committee and NESR staff thank other members of the NESR team (Julia H. Kim, PhD, MPH, RD), Federal staff from USDA and HHS (Dennis Anderson-Villaluz, MBA, RD, LDN, FAND; Hazel Hiza, PhD; Rachel Inman, RD, Tessa Lasswell, MPH, RDN; TusaRebecca Pannucci, PhD, MPH, RD; Elizabeth Rahavi, RD; Kelley Scanlon, PhD, RD; Colleen Sideck, MPH, RDN) and Project Leadership (Eve Stoody, PhD, Janet de Jesus, MS, RD), who supported the Committee by facilitating, executing, and documenting the work necessary to ensure the reviews were completed in accordance with NESR methodology.