# Appendix 3 Excluded articles

The following table lists the articles excluded after full-text screening for this systematic review question. At least 1 reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 6 Articles excluded after full-text screening

| Citation | Rationale
1 | Acosta P, Rojas-Humpire R, Newball-Noriega EE, et al. Dietary practices and nutritional status of children served in a social program for surrogate mothers in Colombia. BMC Nutr. 2023;9:26. doi:10.1186/s40795-023-00685-1. | Study design
2 | Adamo KB, Papadakis S, Dojeiji L, et al. Using path analysis to understand parents’ perceptions of their children’s weight, physical activity and eating habits in the Champlain region of Ontario. Paediatr Child Health. 2010;15:e33-41. doi:10.1093/pch/15.9.e33. | Study design
3 | Adams J, Molyneux M, Squires L. Sustaining an obesity prevention intervention in preschools. Health Promot J Austr. 2011;22:6-10. doi:10.1071/he11006. | Outcome
4 | Afonso L, Castro J, Parente N, et al. A Comprehensive Assessment of Food Parenting Practices: Psychometric Properties of the Portuguese Version of the HomeSTEAD Family Food Practices Survey and Associations with Children’s Weight and Food Intake. Eur J Investig Health Psychol Educ. 2020;10:424-440. doi:10.3390/ejihpe10010032. | Study design
5 | Aguirre T, Hudson DB, Weber K, et al. Mexican American mothers’ eating and child feeding behaviors. Issues Compr Pediatr Nurs. 2012;35:4-23. doi:10.3109/01460862.2012.646462. | Study design; Outcome
6 | Ahmad N, Shariff ZM, Mukhtar F, Lye MS. Effect of Family-Based REDUCE Intervention Program on Children Eating Behavior and Dietary Intake: Randomized Controlled Field Trial. Nutrients. 2020;12(10):3065. Published 2020 Oct 8. doi:10.3390/nu12103065 | Intervention/exposure
7 | Alexandrou C, Henriksson H, Henström M, et al. Effectiveness of a Smartphone App (MINISTOP 2.0) integrated in primary child health care to promote healthy diet and physical activity behaviors and prevent obesity in preschool-aged children: randomized controlled trial. Int J Behav Nutr Phys Act. 2023;20:22. doi:10.1186/s12966-023-01405-5. | Intervention/exposure
8 | Al-Hamidi S. Exploring the Relationship of Parental and Home Influence on the Dietary Intake of Saudi Arabian Children Aged 6-12 Year. Exploring the Relationship of Parental & Home Influence on the Dietary Intake of Saudi Arabian Children Aged 6-12 Year. [Doctoral dissertation]. Washington, DC, Catholic University of America; 2017. | Study design; Publication status
9 | Ali HI, Magriplis E, Attlee A, Al Dhaheri AS, Cheikh Ismail L, Stojanovska L. Feeding Practices of Infants and Toddlers by Their Mothers in Selected Northern Emirates of the United Arab Emirates. Nutrients. 2022;14(18):3719. Published 2022 Sep 9. doi:10.3390/nu14183719 | Study design; Outcome
10 | Alia KA, Wilson DK, St George SM, et al. Effects of parenting style and parent-related weight and diet on adolescent weight status. J Pediatr Psychol. 2013;38:321-9. doi:10.1093/jpepsy/jss127. | Study design
11 | Allirot X, da Quinta N, Chokupermal K, et al. Involving children in cooking activities: A potential strategy for directing food choices toward novel foods containing vegetables. Appetite. 2016;103:275-285. doi:10.1016/j.appet.2016.04.031. | Intervention/exposure
12 | Allirot X, Maiz E, Urdaneta E. Shopping for food with children: A strategy for directing their choices toward novel foods containing vegetables. Appetite. 2018;120:287-296. doi:10.1016/j.appet.2017.09.008. | Intervention/exposure
13 | Alm S, Olsen SO, Honkanen P. The role of family communication and parents’ feeding practices in children’s food preferences. Appetite. 2015;89:112-121. doi:10.1016/j.appet.2015.02.002. | Study design
14 | Alsharairi NA, Somerset SM. Associations between parenting styles and children’s fruit and vegetable intake. Ecol Food Nutr. 2015;54:93-113. doi:10.1080/03670244.2014.953248. | Intervention/exposure; Outcome
15 | Ambrosini GL, Oddy WH, Robinson M, et al. Adolescent dietary patterns are associated with lifestyle and family psycho-social factors. Public Health Nutr. 2009;12:1807-15. doi:10.1017/s1368980008004618. | Study design; Intervention/exposure
16 | Amuta AO, Jacobs W, Idoko EE, et al. Influence of the Home Food Environment on Children’s Fruit and Vegetable Consumption: A Study of Rural Low-Income Families. Health Promot Pract. 2015;16:689-98. doi:10.1177/1524839915589733. | Study design
17 | Andaya AA, Arredondo EM, Alcaraz JE, et al. The association between family meals, TV viewing during meals, and fruit, vegetables, soda, and chips intake among Latino children. J Nutr Educ Behav. 2011;43:308-15. doi:10.1016/j.jneb.2009.11.005. | Study design
18 | Andersen LB, Mølgaard C, Michaelsen KF, et al. Indicators of dietary patterns in Danish infants at 9 months of age. Food Nutr Res. 2015;59:27665. doi:10.3402/fnr.v59.27665. | Study design; Intervention/exposure
19 | Aponte CA, Romanczyk RG. Assessment of feeding problems in children with autism spectrum disorder. Research in Autism Spectrum Disorders. 2016;21:61-72. doi:10.1016/j.rasd.2015.09.007. | Health status
20 | Arcan C, Friend S, Flattum CF, et al. Fill “half your child’s plate with fruits and vegetables”: Correlations with food-related practices and the home food environment. Appetite. 2019;133:77-82. doi:10.1016/j.appet.2018.10.017. | Study design
21 | Arcan C, Hannan PJ, Fulkerson JA, et al. Associations of home food availability, dietary intake, screen time and physical activity with BMI in young American-Indian children. Public Health Nutr. 2013;16:146-55. doi:10.1017/s136898001200033x. | Outcome
22 | Arcan C, Neumark-Sztainer D, Hannan P, et al. Parental eating behaviours, home food environment and adolescent intakes of fruits, vegetables and dairy foods: longitudinal findings from Project EAT. Public Health Nutr. 2007;10:1257-65. doi:10.1017/s1368980007687151. | Age of some participants at I/E
23 | Arlinghaus K, Vollrath K, Dholakia R, et al. Authoritative Parent Feeding Style is Associated with Better Child Diet Quality at Dinner. Journal of the Academy of Nutrition & Dietetics. 2017;117:A145-A145. doi:10.1016/j.jand.2017.08.100. | Publication status
24 | Arlinghaus KR, Vollrath K, Hernandez DC, et al. Authoritative parent feeding style is associated with better child dietary quality at dinner among low-income minority families. Am J Clin Nutr. 2018;108:730-736. doi:10.1093/ajcn/nqy142. | Study design
25 | Arredondo EM, Ayala GX, Soto S, et al. Latina mothers as agents of change in children’s eating habits: findings from the randomized controlled trial Entre Familia: Reflejos de Salud. Int J Behav Nutr Phys Act. 2018;15:95. doi:10.1186/s12966-018- 0714-0. | Age of some participants at I/E
26 | Arrizabalaga-López M, Rada-Fernández de Jáuregui D, Portillo MDP, et al. A theory-based randomized controlled trial in promoting fruit and vegetable intake among schoolchildren: PROFRUVE study. Eur J Nutr. 2020;59:3517-3526. doi:10.1007/s00394- 020-02185-5. | Intervention/exposure
27 | Arvidsson L, Bogl LH, Eiben G, et al. Fat, sugar and water intakes among families from the IDEFICS intervention and control groups: first observations from I.Family. Obes Rev. 2015;16 Suppl 2:127-37. doi:10.1111/obr.12325. | Intervention/exposure
28 | Asigbee FM, Davis JN, Markowitz AK, et al. The Association Between Child Cooking Involvement in Food Preparation and Fruit and Vegetable Intake in a Hispanic Youth Population. Curr Dev Nutr. 2020;4:nzaa028. doi:10.1093/cdn/nzaa028. | Study design; Intervention/exposure
29 | Attorp A, Scott JE, Yew AC, et al. Associations between socioeconomic, parental and home environment factors and fruit and vegetable consumption of children in grades five and six in British Columbia, Canada. BMC Public Health. 2014;14:150. doi:10.1186/1471-2458-14-150. | Study design
30 | Austin EW, Austin B, Kaiser CK, et al. A Media Literacy-Based Nutrition Program Fosters Parent-Child Food Marketing Discussions, Improves Home Food Environment, and Youth Consumption of Fruits and Vegetables. Child Obes. 2020;16:S33-s43. doi:10.1089/chi.2019.0240. | Intervention/exposure
31 | Austin EW, Austin BW, Kaiser CK. Effects of Family-Centered Media Literacy Training on Family Nutrition Outcomes. Prev Sci. 2020;21:308-318. doi:10.1007/s11121-020-01101-x. | Intervention/exposure; Outcome
32 | Avila B, Contreras D, Mobley AR, et al. Are Parental Rules Associated with Low-Income Rural Children’s Consumption of Fruits and Vegetables in the Midwest?. Journal of Hunger and Environmental Nutrition. 2017;12:544-553. doi:10.1080/19320248.2016.1255695. | Study design
33 | Azevedo J, Padrão P, Gregório MJ, et al. A Web-Based Gamification Program to Improve Nutrition Literacy in Families of 3- to 5-Year-Old Children: The Nutriscience Project. J Nutr Educ Behav. 2019;51:326-334. doi:10.1016/j.jneb.2018.10.008. | Intervention/exposure; Outcome
34 | Bailey-Davis L, Poulsen MN, Hirsch AG, et al. Home Food Rules in Relation to Youth Eating Behaviors, Body Mass Index, Waist Circumference, and Percent Body Fat. J Adolesc Health. 2017;60:270-276. doi:10.1016/j.jadohealth.2016.09.020. | Study design
35 | Baker K, Figueroa R. Motivation, Attitudes, and Diet Quality Among US Parents and Adolescents. Am J Health Behav. 2021;45:125-137. doi:10.5993/ajhb.45.1.10. | Study design
36 | Bakırcı-Taylor AL, Reed DB, McCool B, et al. mHealth Improved Fruit and Vegetable Accessibility and Intake in Young Children. J Nutr Educ Behav. 2019;51:556-566. doi:10.1016/j.jneb.2018.11.008. | Intervention/exposure; Outcome
37 | Ball K, MacFarlane A, Crawford D, et al. Can social cognitive theory constructs explain socio-economic variations in adolescent eating behaviours? A mediation analysis. Health Educ Res. 2009;24:496-506. doi:10.1093/her/cyn048. | Study design
38 | Baltaci A, Alvarez de Davila S, Reyes Peralta AO, et al. Adolescent-Reported Latino Fathers’ Food Parenting Practices and Family Meal Frequency Are Associated with Better Adolescent Dietary Intake. Int J Environ Res Public Health. 2021;18(15):8226. Published 2021 Aug 3. doi:10.3390/ijerph18158226 | Study design
39 | Baltaci A, Hurtado Choque GA, Davey C, et al. Padres Preparados, Jóvenes Saludables: A Randomized Controlled Trial to Test Effects of a Community-Based Intervention on Latino Father’s Parenting Practices. Nutrients. 2022;14(23):4967. Published 2022 Nov 23. doi:10.3390/nu14234967 | Intervention/exposure; Outcome
40 | Baltaci A, Hurtado Choque GA, Davey C, et al. Padres Preparados, Jóvenes Saludables: intervention impact of a randomized controlled trial on Latino father and adolescent energy balance-related behaviors. BMC Public Health. 2022;22:1932. doi:10.1186/s12889-022-14284-5. | Intervention/exposure
41 | Baltaci A, Laska MN, Horning M, et al. Parent meal self-efficacy and practices in households with healthy home food environments in the face of economic hardship. Appetite. 2023;190:107029. doi:10.1016/j.appet.2023.107029. | Study design
42 | Bante H, Elliott M, Harrod A, et al. The use of inappropriate feeding practices by rural parents and their effect on preschoolers’ fruit and vegetable preferences and intake. J Nutr Educ Behav. 2008;40:28-33. doi:10.1016/j.jneb.2007.02.007. | Study design
43 | Baranowski T, Baranowski J, Cullen KW, et al. 5 a day Achievement Badge for African-American Boy Scouts: pilot outcome results. Prev Med. 2002;34:353-63. doi:10.1006/pmed.2001.0989. | Intervention/exposure
44 | Baranowski T, Baranowski JC, Cullen KW, et al. The Fun, Food, and Fitness Project (FFFP): the Baylor GEMS pilot study. Ethn Dis. 2003;13:S30-9. | Intervention/exposure
45 | Baranowski T, Beltran A, Chen TA, et al. Predicting Use of Ineffective Responsive, Structure and Control Vegetable Parenting Practices with the Model of Goal Directed Behavior. J Food Res. 2013;2:80-88. doi:10.5539/jfr.v2n6p80. | Study design
46 | Baranowski T, Chen TA, O’Connor T, et al. Dimensions of vegetable parenting practices among preschoolers. Appetite. 2013;69:89-93. doi:10.1016/j.appet.2013.05.015. | Study design
47 | Barbosa C, Lopes C, Costa A, et al. Parental child-feeding practices at 4 years of age are associated with dietary patterns of 7-year-olds. J Hum Nutr Diet. 2023;36:1339-1348. doi:10.1111/jhn.13151. | Outcome
48 | Barragan M, Luna V, Hammons AJ, et al. Reducing Obesogenic Eating Behaviors in Hispanic Children through a Family-Based, Culturally-Tailored RCT: Abriendo Caminos. Int J Environ Res Public Health. 2022;19(4):1917. Published 2022 Feb 9. doi:10.3390/ijerph19041917 | Intervention/exposure
49 | Barros L, Lopes C, Oliveira A. Child and family characteristics are associated with a dietary variety index in 4-year-old children from the Generation XXI cohort. Nutr Res.2019;63:76-85. doi:10.1016/j.nutres.2018.12.001. | Intervention/exposure; Outcome
50 | Barton JM. Food and beverage offerings by parents of preschoolers: A daily survey study of dinner offerings during COVID-19. Appetite. 2022;174:106047. doi:10.1016/j.appet.2022.106047. | Study design; Intervention/exposure
51 | Bassett-Gunter RL, Levy-Milne R, Naylor PJ, et al. A comparison of Theory of Planned Behavior beliefs and healthy eating between couples without children and first-time parents. J Nutr Educ Behav. 2015;47:216-24. doi:10.1016/j.jneb.2015.01.003. | Intervention/exposure; Outcome
52 | Bauer KW, Neumark-Sztainer D, Fulkerson JA, et al. Familial correlates of adolescent girls’ physical activity, television use, dietary intake, weight, and body composition. Int J Behav Nutr Phys Act. 2011;8:25. doi:10.1186/1479-5868-8-25. | Study design
53 | Bauer KW, Neumark-Sztainer D, Hannan PJ, et al. Relationships between the family environment and school-based obesity prevention efforts: can school programs help adolescents who are most in need?. Health Education Research. 2011;26:675-688. doi:10.1093/her/cyr027. | Study design; Intervention/exposure; Outcome
54 | Beck AL, Fernandez A, Rojina J, et al. Randomized Controlled Trial of a Clinic-Based Intervention to Promote Healthy Beverage Consumption Among Latino Children. Clin Pediatr (Phila). 2017;56:838-844. doi:10.1177/0009922817709796. | Intervention/exposure
55 | Beck AL, Mora R, Joseph G, et al. A Multimethod Evaluation of the Futuros Fuertes Intervention to Promote Healthy Feeding, Screen Time, and Sleep Practices. Acad Pediatr. 2023;23:1351-1360. doi:10.1016/j.acap.2023.05.006. | Intervention/exposure
56 | Beck J, De Witt P, McNally J, et al. Predictors of meeting physical activity and fruit and vegetable recommendations in 9-11-year-old children. Health Educ J. 2015;74:183-196. doi:10.1177/0017896913518315. | Study design
57 | Beinert C, Hernes S, Haugen M, et al. No long-term effect of a 2-days intervention on how to prepare homemade food, on toddlers’ skepticism for new food and intake of fruits and vegetables and sweet beverages: a randomized, controlled trial. BMC Res Notes. 2017;10:607. doi:10.1186/s13104-017-2931-z. | Intervention/exposure
58 | Beltran A, Demet R, Hughes SO, et al. Selection and use of vegetable parenting practices did not vary by parent feeding styles: Mixed methods investigation. Appetite. 2022;170:105883. doi:10.1016/j.appet.2021.105883. | Study design; Outcome
59 | Beltran Alicia, Hingle MelanieD, Knesek Jessica, et al. Identifying and Clarifying Values and Reason Statements That Promote Effective Food Parenting Practices, Using Intensive Interviews. Journal of Nutrition Education & Behavior. 2011;43:531-535. doi:10.1016/j.jneb.2011.03.140. | Study design
60 | Bender MS, Nader PR, Kennedy C, et al. A culturally appropriate intervention to improve health behaviors in Hispanic mother-child dyads. Child Obes. 2013;9:157-63. doi:10.1089/chi.2012.0118. | Study design
61 | Bensley RJ, Anderson JV, Brusk JJ, et al. Impact of internet vs traditional Special Supplemental Nutrition Program for Women, Infants, and Children nutrition education on fruit and vegetable intake. J Am Diet Assoc. 2011;111:749-55. doi:10.1016/j.jada.2011.02.010. | Intervention/exposure
62 | Bere E, Glomnes ES, te Velde SJ, et al. Determinants of adolescents’ soft drink consumption. Public Health Nutr. 2008;11:49-56. doi:10.1017/s1368980007000122. | Study design
63 | Bere E, Klepp KI. Correlates of fruit and vegetable intake among Norwegian schoolchildren: parental and self-reports. Public Health Nutr. 2004;7:991-8. doi:10.1079/phn2004619. | Study design
64 | Bere E, Veierød MB, Bjelland M, et al. Free school fruit--sustained effect 1 year later. Health Educ Res. 2006;21:268-75. doi:10.1093/her/cyh063. | Study design; Intervention/exposure
65 | Berge JM, Fertig AR, Trofholz A, et al. Real-time predictors of food parenting practices and child eating behaviors in racially/ethnically diverse families. Int J Behav Nutr Phys Act. 2023;20:86. doi:10.1186/s12966-023-01476-4. | Outcome
66 | Berge JM, Hazzard VM, Larson N, et al. Are there protective associations between family/shared meal routines during COVID-19 and dietary health and emotional well-being in diverse young adults?. Prev Med Rep. 2021;24:101575.doi:10.1016/j.pmedr.2021.101575. | Study design
67 | Berge JM, Hazzard VM, Trofholz A, et al. Longitudinal associations between family meal quality and quantity: Does one matter more for child, parent, and family health and well-being or are they synergistic?. Appetite. 2023;191:107080. doi:10.1016/j.appet.2023.107080. | Age of some participants at I/E
68 | Berge JM, MacLehose RF, Loth KA, et al. Family meals. Associations with weight and eating behaviors among mothers and fathers. Appetite. 2012;58:1128-35. doi:10.1016/j.appet.2012.03.008. | Study design
69 | Berge JM, MacLehose RF, Meyer C, et al. He Said, She Said: Examining Parental Concordance on Home Environment Factors and Adolescent Health Behaviors and Weight Status. J Acad Nutr Diet. 2016;116:46-60. doi:10.1016/j.jand.2015.05.004. | Study design
70 | Berge JM, Miller J, Watts A, et al. Intergenerational transmission of family meal patterns from adolescence to parenthood: longitudinal associations with parents’ dietary intake, weight-related behaviours and psychosocial well-being. Public Health Nutr. 2018;21:299- 308. doi:10.1017/s1368980017002270. | Age of some participants at I/E
71 | Berge JM, Trofholz AC, Aqeel M, et al. A three-arm randomized controlled trial using ecological momentary intervention, community health workers, and video feedback at family meals to improve child cardiovascular health: the Family Matters study design. BMC Public Health. 2023;23:708. doi:10.1186/s12889-023-15504-2. | Study design; Publication status
72 | Berge JM, Wall M, Larson N, et al. Family functioning: associations with weight status, eating behaviors, and physical activity in adolescents. J Adolesc Health. 2013;52:351-7. doi:10.1016/j.jadohealth.2012.07.006. | Study design
73 | Berge JM, Wall M, Larson N, et al. Youth dietary intake and weight status: healthful neighborhood food environments enhance the protective role of supportive family home environments. Health Place. 2014;26:69-77. doi:10.1016/j.healthplace.2013.11.007. | Study design
74 | Berge JM, Wall M, Loth K, et al. Parenting style as a predictor of adolescent weight and weight-related behaviors. J Adolesc Health. 2010;46:331-8. doi:10.1016/j.jadohealth.2009.08.004. | Intervention/exposure
75 | Berger PK, Hohman EE, Marini ME, et al. Girls’ picky eating in childhood is associated with normal weight status from ages 5 to 15 y. Am J Clin Nutr. 2016;104:1577-1582. doi:10.3945/ajcn.116.142430. | Intervention/exposure; Outcome
76 | Berry DC, Schwartz TA, McMurray RG, et al. The family partners for health study: a cluster randomized controlled trial for child and parent weight management. Nutr Diabetes. 2014;4:e101. doi:10.1038/nutd.2013.42. | Intervention/exposure
77 | Best JR, Goldschmidt AB, Mockus-Valenzuela DS, et al. Shared weight and dietary changes in parent-child dyads following family-based obesity treatment. Health Psychol. 2016;35:92-5. doi:10.1037/hea0000247. | Study design; Intervention/exposure
78 | Bevelander KE, Burk WJ, Smit CR, et al. Exploring the directionality in the relationship between descriptive and injunctive parental and peer norms and snacking behavior in a three-year-cross-lagged study. Int J Behav Nutr Phys Act. 2020;17:76. doi:10.1186/s12966-020-00977-w. | Intervention/exposure
79 | Bishop W, Chavarin C, Gonzales HA, et al. Healthy eating and physical activity among low-income Hispanic adolescents and a school-based intervention. Children & Youth Services Review. 2018;86:151-156. doi:10.1016/j.childyouth.2018.01.037. | Intervention/exposure
80 | Bjelland M, Hausken SE, Bergh IH, et al. Changes in adolescents’ and parents’ intakes of sugar-sweetened beverages, fruit and vegetables after 20 months: results from the HEIA study - a comprehensive, multi-component school-based randomized trial. Food Nutr Res. 2015;59:25932. doi:10.3402/fnr.v59.25932. | Intervention/exposure
81 | Bjelland M, Lien N, Grydeland M, et al. Intakes and perceived home availability of sugar-sweetened beverages, fruit and vegetables as reported by mothers, fathers and adolescents in the HEIA (HEalth In Adolescents) study. Public Health Nutr. 2011;14:2156-65. doi:10.1017/s1368980011000917. | Study design
82 | Black MM, Hager ER, Wang Y, et al. Toddler obesity prevention: A two-generation randomized attention-controlled trial. Matern Child Nutr. 2021;17:e13075. doi:10.1111/mcn.13075. | Age of some participants at I/E
83 | Blissett J, Bennett C, Fogel A, et al. Parental modelling and prompting effects on acceptance of a novel fruit in 2-4-year-old children are dependent on children’s foodresponsiveness. Br J Nutr. 2016;115:554-64. doi:10.1017/s0007114515004651. | Study design; Outcome
84 | Blissett J, Haycraft E, Farrow C. Inducing preschool children’s emotional eating: relations with parental feeding practices. Am J Clin Nutr. 2010;92:359-65. doi:10.3945/ajcn.2010.29375. | Study design; Outcome
85 | Blitstein JL, Snider J, Evans WD. Perceptions of the food shopping environment are associated with greater consumption of fruits and vegetables. Public Health Nutr. 2012;15:1124-9. doi:10.1017/s1368980012000523. | Study design
86 | Blom-Hoffman J, Wilcox KR, Dunn L, et al. Family Involvement in School-Based Health Promotion: Bringing Nutrition Information Home. School Psych Rev. 2008;37:567-577. | Intervention/exposure
87 | Bogart LM, Elliott MN, Ober AJ, et al. Home Sweet Home: Parent and Home Environmental Factors in Adolescent Consumption of Sugar-Sweetened Beverages. Acad Pediatr. 2017;17:529-536. doi:10.1016/j.acap.2017.01.015. | Study design
88 | Boles RE, Burdell A, Johnson SL, et al. Home food and activity assessment. Development and validation of an instrument for diverse families of young children. Appetite. 2014;80:23-7. doi:10.1016/j.appet.2014.04.026. | Study design
89 | Boots SB, Tiggemann M, Corsini N. Pumpkin is “yucky”!: A prospective study of overt and covert restriction in the development of young children’s food preferences. Appetite. 2019;135:54-60. doi:10.1016/j.appet.2018.12.035. | Outcome
90 | Borger C, Paolicelli CP, Sun B. Duration of Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) Participation is Associated With Children’s Diet Quality at Age 3 Years. Am J Prev Med. 2022;62:e343-e350. doi:10.1016/j.amepre.2021.12.019. | Intervention/exposure
91 | Borloz S, Bucher Della Torre S, Collet TH, et al. Consumption of Ultraprocessed Foods in a Sample of Adolescents With Obesity and Its Association With the Food Educational Style of Their Parent: Observational Study. JMIR Pediatr Parent. 2021;4:e28608. doi:10.2196/28608. | Study design
92 | Bouhlal S, McBride CM, Ward DS, et al. Drivers of overweight mothers’ food choice behaviors depend on child gender. Appetite. 2015;84:154-60. doi:10.1016/j.appet.2014.09.024. | Intervention/exposure; Outcome
93 | Boutelle KN, Birkeland RW, Hannan PJ, et al. Associations between maternal concern for healthful eating and maternal eating behaviors, home food availability, and adolescent eating behaviors. J Nutr Educ Behav. 2007;39:248-56. doi:10.1016/j.jneb.2007.04.179. | Study design; Outcome
94 | Boutelle KN, Birnbaum AS, Lytle LA, et al. Associations between perceived family meal environment and parent intake of fruit, vegetables, and fat. J Nutr Educ Behav. 2003;35:24-9. doi:10.1016/s1499-4046(06)60323-0. | Study design
95 | Bova A, Arcidiacono F. “You must eat the salad because it is nutritious”. Argumentative strategies adopted by parents and children in food-related discussions at mealtimes. Appetite. 2014;73:81-94. doi:10.1016/j.appet.2013.10.019. | Study design
96 | Branscum P, Housely A. Differences in How Mothers and Fathers Monitor Sugar-Sweetened Beverages for Their Young Children (7-12 Years). Health Educ Behav. 2018;45:247-253. doi:10.1177/1090198117732111. | Study design
97 | Branscum P, Keysor P. Defining Parenting Practices for Reducing Sugar-Sweetened Beverage Consumption Among Preschoolers. Health Promot Pract. 2024;25(2):204-212. doi:10.1177/15248399221135109 | Study design
98 | Branscum P, Lora K, Hernandez DC. Examining Determinants and Co-associations Between Fruit and Vegetable and Sugar-Sweetened Beverage Monitoring Practices Among a Sample of Low-Income Hispanic Mothers. J Racial Ethn Health Disparities. 2020;7:650-659. doi:10.1007/s40615-019-00695-5. | Study design
99 | Branscum P, Lora K. Determinants of Parenting Practices Related to Monitoring Sugar Sweetened Beverages Among Hispanic Mothers. J Immigr Minor Health. 2020;22:120- 125. doi:10.1007/s10903-019-00875-9. | Study design
100 | Branscum P, Lora K. Using the Integrative Behavioral Model to Predict Monitoring of Fruit and Vegetable Consumption Among Hispanic Mothers. Fam Community Health.2017;40:32-38. doi:10.1097/fch.0000000000000130. | Study design
101 | Braun A, Portner J, Xu M, et al. Preliminary Support for the Use of Motivational Interviewing to Improve Parent/Adult Caregiver Behavior for Obesity and Cancer Prevention. Int J Environ Res Public Health. 2023;20(6):4726. Published 2023 Mar 7. doi:10.3390/ijerph20064726 | Intervention/exposure
102 | Briley ME, Ranjit N, Hoelscher DM, et al. Unbundling outcomes of a multilevel intervention to increase fruit, vegetables, and whole grains parents pack for their preschool children in sack lunches. Am J Health Educ. 2012;43:135-142. doi:10.1080/19325037.2012.10599230. | Intervention/exposure
103 | Brock DP, Yuhas M, Porter KJ, et al. Outcomes of a Caregiver-Focused Short Message Service (SMS) Intervention to Reduce Intake of Sugar-Sweetened Beverages in Rural Caregivers and Adolescents. Nutrients. 2023;15(8):1957. Published 2023 Apr 19. doi:10.3390/nu15081957 | Intervention/exposure
104 | Brown M, Roman NV. Nutritional Knowledge, Parenting Styles and Feeding Practices of a South African Sample of Parents. Ecol Food Nutr. 2019;58:529-547. doi:10.1080/03670244.2019.1641800. | Study design
105 | Brown StephenL, Teufel James, Gautam YubaR, et al. Family and Personal Predictors of Early Adolescent Eating Patterns. Californian Am J Health Educ. 2012;10:74-80. | Study design
106 | Bucher Della Torre S, Dudley-Martin F, Kruseman M. ‘Croque&bouge’: A feasible and acceptable programme for obesity prevention in preschoolers at risk and their parents. SAGE Open Med. 2015;3:2050312115574365. doi:10.1177/2050312115574365. | Intervention/exposure; Outcome
107 | Burgess-Champoux TL, Larson N, Neumark-Sztainer D, et al. Are family meal patterns associated with overall diet quality during the transition from early to middle adolescence?. J Nutr Educ Behav. 2009;41:79-86. doi:10.1016/j.jneb.2008.03.113. | Age of some participants at I/E
108 | Burke MP, Jones SJ, Frongillo EA, et al. Parenting styles are associated with overall child dietary quality within low-income and food-insecure households. Public Health Nutr. 2019;22:2835-2843. doi:10.1017/s1368980019001332. | Study design
109 | Burke MP, Martini LH, Blake CE, et al. Stretching Food and Being Creative: Caregiver Responses to Child Food Insecurity. J Nutr Educ Behav. 2017;49:296-303.e1. doi:10.1016/j.jneb.2016.11.010. | Study design
110 | Burnett AJ, Lacy KE, Russell CG, et al. Groups of mothers based on feeding practices and their associations with dietary quality of pre-school children: A latent profile analysis. Appetite. 2022;168:105754. doi:10.1016/j.appet.2021.105754. | Study design
111 | Burnett AJ, Lamb KE, Spence AC, et al. Associations between feeding practices and child dietary quality, and the moderating effect of child eating behaviours on these associations. Eat Behav. 2021;43:101569. doi:10.1016/j.eatbeh.2021.101569. | Study design
112 | Burnett AJ, Lamb KE, Spence AC, et al. Parenting style as a predictor of dietary score change in children from 4 to 14 years of age. Findings from the Longitudinal Study of Australian Children. Public Health Nutr. 2021;24:6058-6066. doi:10.1017/s1368980021003062. | Outcome
113 | Burrows T, Janet WM, Collins CE. Long-term changes in food consumption trends in overweight children in the HIKCUPS intervention. J Pediatr Gastroenterol Nutr. 2011;53:543-7. doi:10.1097/MPG.0b013e3182274829. | Intervention/exposure
114 | Burrows T, Warren JM, Baur LA, et al. Impact of a Child Obesity intervention on dietary intake and behaviors. Int J Obes (Lond). 2008;32:1481-8. doi:10.1038/ijo.2008.96. | Intervention/exposure
115 | Buyco NG, Dorado JB, Azaña GP, et al. Do school-based nutrition interventions improve the eating behavior of school-age children?. Nutr Res Pract. 2022;16:217-232. doi:10.4162/nrp.2022.16.2.217. | Intervention/exposure
116 | Byrne R, Jansen E, Daniels L. Perceived fussy eating in Australian children at 14 months of age and subsequent use of maternal feeding practices at 2 years. Int J Behav Nutr Phys Act. 2017;14:123. doi:10.1186/s12966-017-0582-z. | Intervention/exposure; Outcome
117 | Caldwell AR, Terhorst L, Skidmore ER, et al. Is frequency of family meals associated with fruit and vegetable intake among preschoolers? A logistic regression analysis. J Hum Nutr Diet. 2018;31:505-512. doi:10.1111/jhn.12531. | Study design
118 | Callender C, Liu Y, Moore CE, et al. The baseline characteristics of parents and African American girls in an online obesity prevention program: A feasibility study. Prev Med Rep. 2017;7:110-115. doi:10.1016/j.pmedr.2017.05.011. | Study design
119 | Calvo-Malvar M, Benítez-Estévez AJ, Leis R, Sánchez-Castro J, Gude F. Changes in Dietary Patterns through a Nutritional Intervention with a Traditional Atlantic Diet: The Galiat Randomized Controlled Trial. Nutrients. 2021;13(12):4233. Published 2021 Nov 25. doi:10.3390/nu13124233 | Intervention/exposure
120 | Cameron AJ, Ball K, Hesketh KD, et al. Variation in outcomes of the Melbourne Infant, Feeding, Activity and Nutrition Trial (InFANT) Program according to maternal education and age. Prev Med. 2014;58:58-63. doi:10.1016/j.ypmed.2013.10.021. | Age of some participants at I/E
121 | Cameron SL, Taylor RW, Heath AL. Development and pilot testing of Baby-Led Introduction to SolidS--a version of Baby-Led Weaning modified to address concerns about iron deficiency, growth faltering and choking. BMC Pediatr. 2015;15:99. Published 2015 Aug 26. doi:10.1186/s12887-015-0422-8 | Outcome
122 | Camier Aurore, Chabanet Claire, Davisse-Paturet Camille, et al. Characterization of Infant Feeding Practices and Related-Family Characteristics in the French Nationwide ELFE Birth Cohort. Nutrients. 2021;13:33-33. doi:10.3390/nu13010033. | Outcome
123 | Campbell KJ, Crawford DA, Ball K. Family food environment and dietary behaviors likely to promote fatness in 5-6 year-old children. Int J Obes (Lond). 2006;30:1272-80. doi:10.1038/sj.ijo.0803266. | Study design
124 | Campbell KJ, Lioret S, McNaughton SA, et al. A parent-focused intervention to reduce infant obesity risk behaviors: a randomized trial. Pediatrics. 2013;131:652-60. doi:10.1542/peds.2012-2576. | Intervention/exposure
125 | Campbell KL, Babiarz A, Wang Y, et al. Factors in the home environment associated with toddler diet: an ecological momentary assessment study. Public Health Nutr. 2018;21:1855-1864. doi:10.1017/s1368980018000186. | Intervention/exposure
126 | Carbert NS, Brussoni M, Geller J, et al. Moderating effects of family environment on overweight/obese adolescents’ dietary behaviours. Appetite. 2019;134:69-77. doi:10.1016/j.appet.2018.12.034. | Study design
127 | Cassinat RA, Bruening M, Crespo NC, et al. Effects of a Community-Based Pilot Intervention on Home Food Availability among U.S. Households. Int J Environ Res Public Health. 2020;17(22):8327. Published 2020 Nov 11. doi:10.3390/ijerph17228327 | Study design; Intervention/exposure; Outcome
128 | Castro DC, Samuels M, Harman AE. Growing healthy kids: a community garden-based obesity prevention program. Am J Prev Med. 2013;44:S193-9. doi:10.1016/j.amepre.2012.11.024. | Intervention/exposure
129 | Caton SJ, Ahern SM, Hetherington MM. Vegetables by stealth. An exploratory study investigating the introduction of vegetables in the weaning period. Appetite. 2011;57:816- 25. doi:10.1016/j.appet.2011.05.319. | Study design
130 | Chan L, Magarey AM, Daniels LA. Maternal feeding practices and feeding behaviors of Australian children aged 12-36 months. Matern Child Health J. 2011;15:1363-71. doi:10.1007/s10995-010-0686-4. | Study design
131 | Chang MW, Nitzke S, Brown R. Design and outcomes of a Mothers In Motion behavioral intervention pilot study. J Nutr Educ Behav. 2010;42:S11-21. doi:10.1016/j.jneb.2010.01.010. | Intervention/exposure
132 | Charneca S, Gomes AI, Branco D, et al. Intake of added sugar, fruits, vegetables, and legumes of Portuguese preschool children: Baseline data from SmartFeeding4Kids randomized controlled trial participants. Front Nutr. 2023;10:1150627. doi:10.3389/fnut.2023.1150627. | Study design
133 | Chawner LR, Blundell-Birtill P, Hetherington MM. Parental intentions to implement vegetable feeding strategies at home: A cross sectional study. Appetite. 2023;181:106387. doi:10.1016/j.appet.2022.106387. | Study design
134 | Chawner LR, Blundell-Birtill P, Hetherington MM. Predictors of vegetable consumption in children and adolescents: analyses of the UK National Diet and Nutrition Survey (2008- 2017). Br J Nutr. 2021;126:295-306. doi:10.1017/s0007114520004109. | Study design
135 | Cheah CS, Van Hook J. Chinese and Korean immigrants’ early life deprivation: an important factor for child feeding practices and children’s body weight in the United States. Soc Sci Med. 2012;74:744-52. doi:10.1016/j.socscimed.2011.10.040. | Study design
136 | Chen B, Kattelmann K, Comstock C, McCormack L, Wey H, Meendering J. Parenting Styles, Food Parenting Practices and Dietary Intakes of Preschoolers. Nutrients.2021;13(10):3630. Published 2021 Oct 16. doi:10.3390/nu13103630 | Study design
137 | Chen J, Weiss S, Heyman MB, et al. The Efficacy of the Web-Based Childhood Obesity Prevention Program in Chinese American Adolescents (Web ABC Study). Journal of adolescent health. 2011;49:148-154. doi:10.1016/j.jadohealth.2010.11.243. | Intervention/exposure
138 | Chen JL, Weiss S, Heyman MB, et al. Efficacy of a child-centred and family-based program in promoting healthy weight and healthy behaviors in Chinese American children: a randomized controlled study. J Public Health (Oxf). 2010;32:219-29. doi:10.1093/pubmed/fdp105. | Intervention/exposure
139 | Chomitz VR, Brown A, Lee V, et al. Healthy Living Behaviors Among Chinese-American Preschool-Aged Children: Results of a Parent Survey. J Immigr Minor Health. 2018;20:926-935. doi:10.1007/s10903-017-0619-z. | Study design
140 | Christofaro DGD, Tebar WR, Mota J, et al. Gender Analyses of Brazilian Parental Eating and Activity With Their Adolescents’ Eating Habits. J Nutr Educ Behav. 2020;52:503-511. doi:10.1016/j.jneb.2019.09.015. | Study design
141 | Chu YL, Storey KE, Veugelers PJ. Involvement in meal preparation at home is associated with better diet quality among Canadian children. J Nutr Educ Behav. 2014;46:304-308. doi:10.1016/j.jneb.2013.10.003. | Study design
142 | Cloutier MM, Wiley J, Wang Z, et al. The Early Childhood Obesity Prevention Program (ECHO): an ecologically-based intervention delivered by home visitors for newborns and their mothers. BMC Public Health. 2015;15:584. doi:10.1186/s12889-015-1897-9. | Study design; Intervention/exposure
143 | Colapinto CK, Fitzgerald A, Taper LJ, et al. Children’s preference for large portions: prevalence, determinants, and consequences. J Am Diet Assoc. 2007;107:1183-90. doi:10.1016/j.jada.2007.04.012. | Study design; Intervention/exposure
144 | Cole NC, Musaad SM, Lee SY, et al. Home feeding environment and picky eating behavior in preschool-aged children: A prospective analysis. Eat Behav. 2018;30:76-82. doi:10.1016/j.eatbeh.2018.06.003. | Outcome
145 | Collins CE, Bucher T, Taylor A, et al. How big is a food portion? A pilot study in Australian families. Health Promot J Austr. 2015;26:83-88. doi:10.1071/he14061. | Study design
146 | Collins LJ, Lacy KE, Campbell KJ, et al. The Predictors of Diet Quality among Australian Children Aged 3.5 Years. J Acad Nutr Diet. 2016;116:1114-1126.e2. doi:10.1016/j.jand.2015.12.014. | Outcome
147 | Colón-Ramos U, Monge-Rojas R, Smith-Castro V, et al. Family function and eating behaviours among Hispanic/Latino youth: results from the Hispanic Community Children’s Health Study/Study of Latino Youth (SOL Youth). Public Health Nutr. 2021;24:924-934. doi:10.1017/s1368980020001457. | Study design
148 | Conlon BA, McGinn AP, Isasi CR, et al. Home Environment Factors and Health Behaviors of Low-income, Overweight, and Obese Youth. Am J Health Behav. 2019;43:420-436. doi:10.5993/ajhb.43.2.17. | Study design
149 | Cooke LJ, Chambers LC, Añez EV, et al. Eating for pleasure or profit: the effect of incentives on children’s enjoyment of vegetables. Psychol Sci. 2011;22:190-6. doi:10.1177/0956797610394662. | Intervention/exposure; Outcome
150 | Coon KA, Goldberg J, Rogers BL, et al. Relationships between use of television during meals and children’s food consumption patterns. Pediatrics. 2001;107:E7. doi:10.1542/peds.107.1.e7. | Study design
151 | Cortés DE, Millán-Ferro A, Schneider K, et al. Food purchasing selection among low-income, Spanish-speaking Latinos. Am J Prev Med. 2013;44:S267-73. doi:10.1016/j.amepre.2012.11.012. | Intervention/exposure; Outcome
152 | Cosco NG, Wells NM, Zhang D, et al. Hands-on childcare garden intervention: A randomized controlled trial to assess effects on fruit and vegetable identification, liking, and consumption among children aged 3-5 years in North Carolina. Front Psychol. 2022;13:993637. doi:10.3389/fpsyg.2022.993637. | Intervention/exposure
153 | Costa D, Warkentin S, Oliveira A. The effect of sugar-sweetened beverages at 4 years of age on appetitive behaviours of 7-year-olds from the Generation XXI birth cohort. Br J Nutr. 2021;126:790-800. doi:10.1017/s000711452000447x. | Intervention/exposure
154 | Costa S, Pinto A, Santos AC, et al. The association of problematic eating behaviours with food quality and body mass index at 7 years of age. Eur J Clin Nutr. 2019;73:549- 557. doi:10.1038/s41430-018-0169-z. | Study design; Intervention/exposure
155 | Coto J, Pulgaron ER, Graziano PA, et al. Parents as Role Models: Associations Between Parent and Young Children’s Weight, Dietary Intake, and Physical Activity in a Minority Sample. Matern Child Health J. 2019;23:943-950. doi:10.1007/s10995-018- 02722-z. | Study design
156 | Couch SC, Glanz K, Zhou C, et al. Home food environment in relation to children’s diet quality and weight status. J Acad Nutr Diet. 2014;114:1569-1579.e1. doi:10.1016/j.jand.2014.05.015. | Study design
157 | Coulthard H, Harris G, Emmett P. Long-term consequences of early fruit and vegetable feeding practices in the United Kingdom. Public Health Nutr. 2010;13:2044-51. doi:10.1017/s1368980010000790. | Intervention/exposure
158 | Coulthard H, Van den Tol AJM, Jeffers S, et al. Music as an alternative self-regulation strategy to snack foods following a negative mood induction in 5-7-year-old children: Interactions with parental use of food as a reward. Appetite. 2023;186:106517. doi:10.1016/j.appet.2023.106517. | Study design; Outcome
159 | Coura CP, Monteiro LS, De Cnop ML, et al. Innovative methods in nutritional interventions through sensory-based workshops with preschool children. Revista de Nutricao. 2022;35: e210227. doi:10.1590/1678-9865202235E210227. | Outcome
160 | Cowbrough K, Cowbrough Kathy. Feeding the toddler: 12 months to 3 years--challenges and opportunities. Journal of Family Health Care. 2010;20:49-52. | Publication status
161 | Cravener TL, Schlechter H, Loeb KL, et al. Feeding Strategies Derived from Behavioral Economics and Psychology Can Increase Vegetable Intake in Children as Part of a Home-Based Intervention: Results of a Pilot Study. J Acad Nutr Diet. 2015;115:1798- 807. doi:10.1016/j.jand.2015.03.024. | Intervention/exposure; Outcome
162 | Crespo NC, Elder JP, Ayala GX, et al. Results of a multi-level intervention to prevent and control childhood obesity among Latino children: the Aventuras Para Niños Study. Ann Behav Med. 2012;43:84-100. doi:10.1007/s12160-011-9332-7. | Intervention/exposure
163 | Cullen KW, Baranowski T, Owens E, et al. Availability, accessibility, and preferences for fruit, 100% fruit juice, and vegetables influence children’s dietary behavior. Health Educ Behav. 2003;30:615-26. doi:10.1177/1090198103257254. | Study design
164 | Cullen KW, Baranowski T, Rittenberry L, et al. Child-reported family and peer influences on fruit, juice and vegetable consumption: reliability and validity of measures. Health Educ Res. 2001;16:187-200. doi:10.1093/her/16.2.187. | Study design
165 | Cullen KW, Klesges LM, Sherwood NE, et al. Measurement characteristics of diet-related psychosocial questionnaires among African-American parents and their 8- to 10- year-old daughters: results from the Girls’ health Enrichment Multi-site Studies. Prev Med. 2004;38 Suppl:S34-42. doi:10.1016/j.ypmed.2003.05.002. | Study design
166 | Cullen KW, Liu Y, Thompson DI. Meal-Specific Dietary Changes From Squires Quest! II: a Serious Video Game Intervention. Journal of nutrition education and behavior. 2016;48:326-330.e1. doi:10.1016/j.jneb.2016.02.004. | Intervention/exposure
167 | Cullen KW, Thompson D, Chen TA. Outcome Evaluation of Family Eats. Health Educ Behav. 2017;44:32-40. doi:10.1177/1090198116643917. | Age of some participants at I/E
168 | Cullen KW, Thompson D. Feasibility of an 8-week African American web-based pilot program promoting healthy eating behaviors: Family Eats. Am J Health Behav. 2008;32:40-51. doi:10.5555/ajhb.2008.32.1.40. | Intervention/exposure; Outcome
169 | Cunningham-Sabo L, Lohse B, Smith S, et al. Fuel for Fun: a cluster-randomized controlled study of cooking skills, eating behaviors, and physical activity of 4th graders and their families. BMC Public Health. 2016;16:444. doi:10.1186/s12889-016-3118-6. | Intervention/exposure; Publication status
170 | Curtin C, Bandini LG, Must A, et al. Parent support improves weight loss in adolescents and young adults with Down syndrome. J Pediatr. 2013;163:1402-8.e1. doi:10.1016/j.jpeds.2013.06.081. | Health status
171 | Cynthia J, Zalilah MS, Lim MY. Relationship between family meals away from home and nutritional status of adolescents. Malays J Nutr. 2013;19:25-35. | Study design
172 | Dallacker M, Knobl V, Hertwig R, et al. Effect of Longer Family Meals on Children’s Fruit and Vegetable Intake: A Randomized Clinical Trial. JAMA Netw Open. 2023;6:e236331.doi:10.1001/jamanetworkopen.2023.6331. | Outcome
173 | Damiano SR, Hart LM, Paxton SJ. Correlates of parental feeding practices with pre-schoolers: Parental body image and eating knowledge, attitudes, and behaviours. Appetite. 2016;101:192-8. doi:10.1016/j.appet.2016.03.008. | Study design
174 | Daniels LA, Mallan KM, Battistutta D, et al. Child eating behavior outcomes of an early feeding intervention to reduce risk indicators for Child Obesity: the NOURISH RCT. Obesity (Silver Spring). 2014;22:E104-11. doi:10.1002/oby.20693. | Age of some participants at I/E
175 | Darfour-Oduro SA, Andrade JE, Grigsby-Toussaint DS. Do Fruit and Vegetable Policies, Socio-Environmental Factors, and Physical Activity Influence Fruit and Vegetable Intake Among Adolescents?. J Adolesc Health. 2020;66:172-180. doi:10.1016/j.jadohealth.2019.07.016. | Study design; Intervention/exposure
176 | Dave JM, Evans AE, Pfeiffer KA, et al. Correlates of availability and accessibility of fruits and vegetables in homes of low-income Hispanic families. Health Educ Res. 2010;25:97- 108. doi:10.1093/her/cyp044. | Study design
177 | Davis AM, Daldalian MC, Mayfield CA, et al. Outcomes from an urban pediatric obesity program targeting minority youth: the Healthy Hawks program. Child Obes. 2013;9:492- 500. doi:10.1089/chi.2013.0053. | Intervention/exposure
178 | De Bock F, Breitenstein L, Fischer JE. Positive impact of a pre-school-based nutritional intervention on children’s fruit and vegetable intake: results of a cluster-randomized trial. Public Health Nutr. 2012;15:466-75. doi:10.1017/s136898001100200x. | Intervention/exposure
179 | De Bourdeaudhuij I, Klepp K, Due P, et al. Reliability and validity of a questionnaire to measure personal, social and environmental correlates of fruit and vegetable intake in 10-11-year-old children in five European countries. Public Health Nutrition. 2005;8:189- 200. doi:10.1079/phn2004673. | Study design
180 | De Bourdeaudhuij I, te Velde S, Brug J, et al. Personal, social and environmental predictors of daily fruit and vegetable intake in 11-year-old children in nine European countries. Eur J Clin Nutr. 2008;62:834-41. doi:10.1038/sj.ejcn.1602794. | Study design
181 | de Bruijn GJ, Kremers SP, de Vries H, et al. Associations of social-environmental and individual-level factors with adolescent soft drink consumption: results from the SMILE study. Health Educ Res. 2007;22:227-37. doi:10.1093/her/cyl066. | Study design
182 | De Coen V, Vansteelandt S, Maes L, et al. Parental socioeconomic status and soft drink consumption of the child. The mediating proportion of parenting practices. Appetite. 2012;59:76-80. doi:10.1016/j.appet.2012.03.024. | Study design
183 | De Lepeleere S, De Bourdeaudhuij I, Cardon G, et al. The effect of an online video intervention ‘Movie Models’ on specific parenting practices and parental self-efficacy related to children’s physical activity, screen-time and healthy diet: a quasi experimental study. BMC Public Health. 2017;17:366. doi:10.1186/s12889-017-4264-1. | Age of some participants at I/E
184 | de Wild VW, de Graaf C, Boshuizen HC, et al. Influence of choice on vegetable intake in children: an in-home study. Appetite. 2015;91:1-6. doi:10.1016/j.appet.2015.03.025. | Intervention/exposure; Outcome
185 | de Winter AF, Visser L, Verhulst FC, et al. Longitudinal patterns and predictors of multiple health risk behaviors among adolescents: The TRAILS study. Prev Med. 2016;84:76-82. doi:10.1016/j.ypmed.2015.11.028. | Intervention/exposure; Outcome
186 | DeJesus JM, Gelman SA, Viechnicki GB, et al. An investigation of maternal food intake and maternal food talk as predictors of child food intake. Appetite. 2018;127:356-363. doi:10.1016/j.appet.2018.04.018. | Study design; Intervention/exposure
187 | Delaney CL, Byrd-Bredbenner C. Family Social Support and Weight-Related Behaviors of School-Age Children: An Exploratory Analysis. Int J Environ Res Public Health. 2022;19(14):8501. Published 2022 Jul 12. doi:10.3390/ijerph19148501 | Study design
188 | Delaney CL, Spaccarotella K, Quick V, Byrd-Bredbenner C. A Comparison of Weight-Related Behaviors of Hispanic Mothers and Children by Acculturation Level. Int J Environ Res Public Health. 2021;18(2):503. Published 2021 Jan 9. doi:10.3390/ijerph18020503 | Study design; Intervention/exposure
189 | Delbosq S, Velasco V, Vercesi C, Gruppo Regionale Hbsc Lombardia, Vecchio LP. Adolescents’ Nutrition: The Role of Health Literacy, Family and Socio-Demographic Variables. Int J Environ Res Public Health. 2022;19(23):15719. Published 2022 Nov 25. doi:10.3390/ijerph192315719 | Study design
190 | Delfino LD, Tebar WR, Silva DAS, Gil FCS, Mota J, Christofaro DGD. Food advertisements on television and eating habits in adolescents: a school-based study. Rev Saude Publica. 2020;54:55. doi:10.11606/s1518-8787.2020054001558 | Study design; Intervention/exposure
191 | Delisle Nyström C, Cameron AJ, Campbell KJ, et al. Variation in outcomes of the Melbourne Infant, Feeding, Activity and Nutrition Trial (INFANT) according to maternal education and age 2 and 3·5 years post-intervention. Public Health Nutr. 2021;24:1460- 1468. doi:10.1017/s1368980021000045. | Intervention/exposure; Comparator
192 | Delisle C, Sandin S, Forsum E, et al. A web- and mobile phone-based intervention to prevent obesity in 4-year-olds (MINISTOP): a population-based randomized controlled trial. BMC Public Health. 2015;15:95. doi:10.1186/s12889-015-1444-8. | Intervention/exposure; Publication status
193 | Deming DM, Briefel RR, Reidy KC. Infant feeding practices and food consumption patterns of children participating in WIC. J Nutr Educ Behav. 2014;46(3 Suppl):S29-S37. doi:10.1016/j.jneb.2014.02.020 | Study design; Intervention/exposure
194 | Demissie Z, Eaton DK, Lowry R, et al. The Association of Meal Practices and Other Dietary Correlates With Dietary Intake Among High School Students in the United States, 2010. Am J Health Promot. 2015;29:e203-13. doi:10.4278/ajhp.131211-QUAN-632. | Study design
195 | Deslippe A L O’ Connor T M, Brussoni M Mâsse L C. The association of food parenting practices with adolescents’ dietary behaviors differ by youth gender, but not by parent gender. Appetite. 2022;169:105846. doi:10.1016/j.appet.2021.105846. | Study design
196 | DeSmet A, Liu Y, De Bourdeaudhuij I, et al. The effectiveness of asking behaviors among 9-11 year-old children in increasing home availability and children’s intake of fruit and vegetables: results from the Squire’s Quest II self-regulation game intervention. Int J Behav Nutr Phys Act. 2017;14:51. doi:10.1186/s12966-017-0506-y. | Age of some participants at I/E
197 | Dickin KL, Hill TF, Dollahite JS. Practice-based evidence of effectiveness in an integrated nutrition and parenting education intervention for low-income parents. J Acad Nutr Diet. 2014;114:945-950. doi:10.1016/j.jand.2013.09.029. | Study design
198 | Dickin KL, Seim G. Adapting the Trials of Improved Practices (TIPs) approach to explore the acceptability and feasibility of nutrition and parenting recommendations: what works for low-income families?. Matern Child Nutr. 2015;11:897-914. doi:10.1111/mcn.12078. | Study design; Outcome
199 | Diep CS, Beltran A, Chen TA, et al. Predicting use of effective vegetable parenting practices with the Model of Goal Directed Behavior. Public Health Nutr. 2015;18:1389- 96. doi:10.1017/s1368980014002079. | Study design; Outcome
200 | Ding D, Sallis JF, Norman GJ, et al. Community food environment, home food environment, and fruit and vegetable intake of children and adolescents. J Nutr Educ Behav. 2012;44:634-8. doi:10.1016/j.jneb.2010.07.003. | Study design
201 | Dinkel D, Tibbits M, Hanigan E, et al. Healthy Families: A Family-Based Community Intervention To Address Childhood Obesity. J Community Health Nurs. 2017;34:190-202. doi:10.1080/07370016.2017.1369808. | Intervention/exposure
202 | Dixon LB, Tershakovec AM, McKenzie J, et al. Diet quality of young children who received nutrition education promoting lower dietary fat. Public Health Nutr. 2000;3:411- 6. doi:10.1017/s1368980000000471. | Intervention/exposure
203 | Do B, Wang SD, Naya CH, et al. Momentary and personal characteristics predicting maternal fruit and vegetable preparation for children using ecological momentary assessment. Eat Behav. 2021;41:101492. doi:10.1016/j.eatbeh.2021.101492. | Outcome
204 | Do B, Yang CH, Lopez NV, et al. Investigating the momentary association between maternal support and children’s fruit and vegetable consumption using ecological momentary assessment. Appetite. 2020;150:104667. doi:10.1016/j.appet.2020.104667. | Age of some participants at I/E
205 | Dos Santos CT, Machado CO, Höfelmann DA. Family meals, diet quality and obesity among adolescents: findings from a school-based study in a capital city of southern Brazil. Minerva Pediatr (Torino). 2024;76(2):180-188. doi:10.23736/S2724- 5276.20.05918-6 | Study design
206 | Drapeau V, Harvey AA, Jacob R, et al. The impact of a family web-based nutrition intervention to increase fruit, vegetable, and dairy intakes: a single-blinded randomized family clustered intervention. Nutr J. 2022;21:75. doi:10.1186/s12937-022-00825-6. | Intervention/exposure
207 | Draxten M, Fulkerson JA, Friend S, et al. Parental role modeling of fruits and vegetables at meals and snacks is associated with children’s adequate consumption. Appetite. 2014;78:1-7. doi:10.1016/j.appet.2014.02.017. | Study design
208 | D’Souza NJ, Downing K, Abbott G, et al. A comparison of children’s diet and movement behaviour patterns derived from three unsupervised multivariate methods. PLoS One.2021;16:e0255203. doi:10.1371/journal.pone.0255203. | Intervention/exposure; Outcome
209 | Dubois L, Diasparra M, Bédard B, et al. Genetic and environmental influences on eating behaviors in 2.5- and 9-year-old children: a longitudinal twin study. Int J Behav Nutr Phys Act. 2013;10:134. doi:10.1186/1479-5868-10-134. | Intervention/exposure; Outcome
210 | Dubois L, Farmer A, Girard M, et al. Social factors and television use during meals and snacks is associated with higher BMI among pre-school children. Public Health Nutr. 2008;11:1267-79. doi:10.1017/s1368980008002887. | Study design; Intervention/exposure
211 | Dulin A, Risica PM, Mello J, et al. Examining neighborhood and interpersonal norms and social support on fruit and vegetable intake in low-income communities. BMC Public Health. 2018;18:455. doi:10.1186/s12889-018-5356-2. | Study design
212 | Dumas AA, Lemieux S, Lapointe A, et al. Long-term effects of a healthy eating blog in mothers and children. Matern Child Nutr. 2020;16:e12981. doi:10.1111/mcn.12981. | Intervention/exposure
213 | Duncanson K, Burrows T, Collins C. Effect of a low-intensity parent-focused nutrition intervention on dietary intake of 2- to 5-year olds. J Pediatr Gastroenterol Nutr. 2013;57:728-34. doi:10.1097/mpg.0000000000000068. | Intervention/exposure
214 | Duncanson K, Lee YQ, Burrows T, et al. Utility of a brief index to measure diet quality of Australian preschoolers in the Feeding Healthy Food to Kids Randomised Controlled Trial. Nutr Diet. 2017;74:158-166. doi:10.1111/1747-0080.12295. | Intervention/exposure
215 | Dunton GF, Dzubur E, Huh J, et al. Daily Associations of Stress and Eating in Mother-Child Dyads. Health Educ Behav. 2017;44:365-369. doi:10.1177/1090198116663132. | Study design; Intervention/exposure
216 | Durão C, Andreozzi V, Oliveira A, et al. Maternal child-feeding practices and dietary inadequacy of 4-year-old children. Appetite. 2015;92:15-23. doi:10.1016/j.appet.2015.04.067. | Study design
217 | Durão C, Severo M, Oliveira A, et al. Association of maternal characteristics and behaviours with 4-year-old children’s dietary patterns. Matern Child Nutr. 2017;13(2):e12278. doi:10.1111/mcn.12278 | Study design; Outcome
218 | Edelson LR, Mokdad C, Martin N. Prompts to eat novel and familiar fruits and vegetables in families with 1-3 year-old children: Relationships with food acceptance and intake. Appetite. 2016;99:138-148. doi:10.1016/j.appet.2016.01.015. | Study design
219 | Edmonds J, Baranowski T, Baranowski J, et al. Ecological and socioeconomic correlates of fruit, juice, and vegetable consumption among African-American boys. Prev Med. 2001;32:476-81. doi:10.1006/pmed.2001.0831. | Study design
220 | Edwards KL, Thomas JM, Higgs S, et al. Exposure to models’ positive facial expressions whilst eating a raw vegetable increases children’s acceptance and consumption of the modelled vegetable. Appetite. 2022;168:105779. doi:10.1016/j.appet.2021.105779. | Intervention/exposure; Outcome
221 | Ek A, Delisle Nyström C, Chirita-Emandi A, et al. A randomized controlled trial for overweight and obesity in preschoolers: the More and Less Europe study - an intervention within the STOP project. BMC Public Health. 2019;19:945. doi:10.1186/s12889-019-7161-y. | Study design
222 | Elder JP, Crespo NC, Corder K, et al. Childhood obesity prevention and control in city recreation centres and family homes: the MOVE/me Muevo Project. Pediatr Obes. 2014;9:218-31. doi:10.1111/j.2047-6310.2013.00164.x. | Intervention/exposure
223 | Elfhag K, Rasmussen F. Food consumption, eating behaviour and self-esteem among single v. married and cohabiting mothers and their 12-year-old children. Public Health Nutr. 2008;11:934-9. doi:10.1017/s1368980008002449. | Study design; Intervention/exposure
224 | Elizondo-Montemayor L, Moreno-Sànchez D, Gutierrez NG, et al. Individualized tailor-made dietetic intervention program at schools enhances eating behaviors and dietary habits in obese Hispanic children of low socioeconomic status. ScientificWorldJournal. 2014;2014:484905. doi:10.1155/2014/484905. | Intervention/exposure
225 | Elliott Elaine, Holly Cheryl, Porter Sallie. Parents and Teachers as Role Models for Healthy Behaviors in Preschoolers. Pediatric Nursing. 2023;49:135-141. | Intervention/exposure
226 | Ellis JM, Galloway AT, Webb RM, et al. Recollections of pressure to eat during childhood, but not picky eating, predict young adult eating behavior. Appetite.2016;97:58-63. doi:10.1016/j.appet.2015.11.020. | Study design; Outcome
227 | Engels HJ, Gretebeck RJ, Gretebeck KA, et al. Promoting healthful diets and exercise: efficacy of a 12-week after-school program in urban African Americans. J Am Diet Assoc. 2005;105:455-9. doi:10.1016/j.jada.2004.12.003. | Intervention/exposure
228 | Entin A, Kaufman-Shriqui V, Naggan L, et al. Parental feeding practices in relation to low diet quality and obesity among LSES children. J Am Coll Nutr. 2014;33:306-14. doi:10.1080/07315724.2013.874936. | Study design
229 | Epstein LH, Gordy CC, Raynor HA, et al. Increasing fruit and vegetable intake and decreasing fat and sugar intake in families at risk for childhood obesity. Obes Res. 2001;9:171-8. doi:10.1038/oby.2001.18. | Intervention/exposure
230 | Epstein LH, Paluch RA, Beecher MD, et al. Increasing healthy eating vs. reducing high energy-dense foods to treat pediatric obesity. Obesity (Silver Spring). 2008;16:318-26. doi:10.1038/oby.2007.61. | Intervention/exposure
231 | Erinosho TO, Beth Dixon L, Young C, et al. Caregiver food behaviours are associated with dietary intakes of children outside the child-care setting. Public Health Nutr. 2013;16:1263-72. doi:10.1017/s136898001200345x. | Study design
232 | Esfarjani F, Khalafi M, Mohammadi F, et al. Family-based intervention for controlling childhood obesity: an experience among Iranian children. Int J Prev Med. 2013;4:358-65. | Intervention/exposure
233 | Evans AE, Dave J, Tanner A, et al. Changing the home nutrition environment: effects of a nutrition and media literacy pilot intervention. Fam Community Health. 2006;29:43-54. doi:10.1097/00003727-200601000-00006. | Intervention/exposure; Outcome
234 | Evans CEL, Greenwood DC, Thomas JD, et al. SMART lunch box intervention to improve the food and nutrient content of children’s packed lunches: UK wide cluster randomised controlled trial. Journal of Epidemiology and Community Health. 2010;64:970-976. doi:10.1136/jech.2008.085837. | Intervention/exposure
235 | Evans WD, Wallace J, Snider J. The 5-4-3-2-1 go! Brand to promote nutrition and physical activity: a case of positive behavior change but negative change in beliefs. J Health Commun. 2015;20:512-20. doi:10.1080/10810730.2014.989344. | Study design; Outcome
236 | Ezendam NP, Evans AE, Stigler MH, et al. Cognitive and home environmental predictors of change in sugar-sweetened beverage consumption among adolescents. Br J Nutr. 2010;103:768-74. doi:10.1017/s0007114509992297. | Age of some participants at I/E
237 | Faber M, Laubscher R, Laurie S. Availability of, access to and consumption of fruits and vegetables in a peri-urban area in KwaZulu-Natal, South Africa. Matern Child Nutr. 2013;9:409-24. doi:10.1111/j.1740-8709.2011.00372.x. | Study design; Intervention/exposure
238 | Faith MS, Dennison BA, Edmunds LS, et al. Fruit juice intake predicts increased adiposity gain in children from low-income families: weight status-by-environment interaction. Pediatrics. 2006;118:2066-75. doi:10.1542/peds.2006-1117. | Study design
239 | Falciglia G, Pabst S, Couch S, et al. Impact of parental food choices on child food neophobia. Children’s Health Care. 2004;33:217-225. doi:10.1207/s15326888chc3303_4. | Study design; Intervention/exposure
240 | Fangupo LJ, Heath ALM, Williams SM, et al. Impact of an early-life intervention on the nutrition behaviors of 2-y-old children: A randomized controlled trial1,2. American Journal of Clinical Nutrition. 2015;102:704-712. doi:10.3945/ajcn.115.111823. | Intervention/exposure
241 | Faught E, Vander Ploeg K, Chu YL, et al. The influence of parental encouragement and caring about healthy eating on children’s diet quality and body weights. Public Health Nutr. 2016;19:822-9. doi:10.1017/s1368980015002049. | Study design; Outcome
242 | Feeley A, Musenge E, Pettifor JM, et al. Changes in dietary habits and eating practices in adolescents living in urban South Africa: the birth to twenty cohort. Nutrition. 2012;28:e1-6. doi:10.1016/j.nut.2011.11.025. | Outcome
243 | Feeley AB, Musenge E, Pettifor JM, et al. Investigation into longitudinal dietary behaviours and household socio-economic indicators and their association with BMI Z-score and fat mass in South African adolescents: the Birth to Twenty (Bt20) cohort. Public Health Nutr. 2013;16:693-703. doi:10.1017/s1368980012003308. | Outcome
244 | Fein SB, Labiner-Wolfe J, Scanlon KS, et al. Selected complementary feeding practices and their association with maternal education. Pediatrics. 2008;122 Suppl 2:S91-7.doi:10.1542/peds.2008-1315l. | Intervention/exposure
245 | Feinberg E, Kavanagh PL, Young RL, et al. Food insecurity and compensatory feeding practices among urban black families. Pediatrics. 2008;122:e854-60. doi:10.1542/peds.2008-0831. | Study design
246 | Feldens CA, Vítolo MR, Maciel RR, et al. Exploring the risk factors for early-life sugar consumption: A birth cohort study. Int J Paediatr Dent. 2021;31:223-230. doi:10.1111/ipd.12713. | Intervention/exposure; Outcome
247 | Feldman S, Eisenberg ME, Neumark-Sztainer D, et al. Associations between watching TV during family meals and dietary intake among adolescents. J Nutr Educ Behav. 2007;39:257-63. doi:10.1016/j.jneb.2007.04.181. | Study design
248 | Feng D, Song H, Esperat MC, et al. A Multicomponent Intervention Helped Reduce Sugar-Sweetened Beverage Intake in Economically Disadvantaged Hispanic Children. Am J Health Promot. 2016;30:594-603. doi:10.4278/ajhp.140801-QUAN-384. | INCLUDE; Intervention/exposure
249 | Ferguson GM, Meeks Gardner JM, Nelson MR, et al. Food-Focused Media Literacy for Remotely Acculturating Adolescents and Mothers: A Randomized Controlled Trial of the “JUS Media? Programme”. J Adolesc Health. 2021;69:1013-1023. doi:10.1016/j.jadohealth.2021.06.006. | Intervention/exposure
250 | Fernandez C, DeJesus JM, Miller AL, et al. Selective eating behaviors in children: An observational validation of parental report measures. Appetite. 2018;127:163-170. doi:10.1016/j.appet.2018.04.028. | Outcome
251 | Fernando NNT, Campbell KJ, McNaughton SA, Zheng M, Lacy KE. Predictors of Dietary Energy Density among Preschool Aged Children. Nutrients. 2018;10(2):178. Published 2018 Feb 6. doi:10.3390/nu10020178 | Outcome
252 | Ferreira VR, Sangalli CN, Leffa PS, et al. The impact of a primary health care intervention on infant feeding practices: a cluster randomised controlled trial in Brazil. J Hum Nutr Diet. 2019;32:21-30. doi:10.1111/jhn.12595. | Intervention/exposure
253 | Fertig AR, Loth KA, Trofholz AC, et al. Compared to Pre-prepared Meals, Fully and Partly Home-Cooked Meals in Diverse Families with Young Children Are More Likely to Include Nutritious Ingredients. J Acad Nutr Diet. 2019;119:818-830. doi:10.1016/j.jand.2018.12.006. | Study design; Intervention/exposure
254 | Fiese BH, Barton JM, Sahin E. Longitudinal changes in home food availability across the first 3 years of life and associations with family context predictors. Front Nutr. 2023;10:1215894. doi:10.3389/fnut.2023.1215894. | Outcome
255 | Fildes A, Lopes C, Moreira P, et al. An exploratory trial of parental advice for increasing vegetable acceptance in infancy. Br J Nutr. 2015;114:328-36. doi:10.1017/s0007114515001695. | Outcome; Age at outcome
256 | Fildes A, van Jaarsveld CH, Llewellyn CH, et al. Nature and nurture in children’s food preferences. Am J Clin Nutr. 2014;99:911-7. doi:10.3945/ajcn.113.077867. | Intervention/exposure; Outcome
257 | Fildes A, van Jaarsveld CHM, Wardle J, et al. Parent-administered exposure to increase children’s vegetable acceptance: a randomized controlled trial. J Acad Nutr Diet. 2014;114:881-888. doi:10.1016/j.jand.2013.07.040. | Intervention/exposure
258 | Fink SK, Racine EF, Mueffelmann RE, et al. Family meals and diet quality among children and adolescents in North Carolina. J Nutr Educ Behav. 2014;46:418-22. doi:10.1016/j.jneb.2014.05.004. | Study design
259 | Fischer C, Brug J, Tak NI, et al. Differences in fruit and vegetable intake and their determinants among 11-year-old schoolchildren between 2003 and 2009. Int J Behav Nutr Phys Act. 2011;8:141. doi:10.1186/1479-5868-8-141. | Study design
260 | Fisher JO, Mitchell DC, Smiciklas-Wright H, et al. Parental influences on young girls’ fruit and vegetable, micronutrient, and fat intakes. J Am Diet Assoc. 2002;102:58-64. doi:10.1016/s0002-8223(02)90017-9. | Study design
261 | Fitriana Dona Muji, Arief Yuni Sufyanti, Krisnana Ilya. The Correlation Between Parents’ Self-Determination with Behavioral Prevention of Picky Eating in Toddlers. Indonesian Nursing Journal of Education & Clinic (INJEC). 2020;5:164-169. doi:10.24990/injec.v5i2.310. | Study design
262 | Flattum C, Draxten M, Horning M, et al. HOME Plus: Program design and implementation of a family-focused, community-based intervention to promote the frequency and healthfulness of family meals, reduce children’s sedentary behavior, andprevent obesity. Int J Behav Nutr Phys Act. 2015;12:53. doi:10.1186/s12966-015-0211-7. | Intervention/exposure; Outcome
263 | Fletcher A, Wolfenden L, Wyse R, et al. A randomised controlled trial and mediation analysis of the ‘Healthy Habits’, telephone-based dietary intervention for preschool children. Int J Behav Nutr Phys Act. 2013;10:43. doi:10.1186/1479-5868-10-43. | Outcome
264 | Fletcher S, Wright C, Jones A, Parkinson K, Adamson A. Tracking of toddler fruit and vegetable preferences to intake and adiposity later in childhood. Matern Child Nutr. 2017;13(2):e12290. doi:10.1111/mcn.12290 | Intervention/exposure
265 | Flores-Barrantes P, Iglesia I, Cardon G, et al. Longitudinal Associations between Food Parenting Practices and Dietary Intake in Children: The Feel4Diabetes Study. Nutrients. 2021;13(4):1298. Published 2021 Apr 14. doi:10.3390/nu13041298 | Age of some participants at I/E
266 | Flores-Barrantes P, Mavrogianni C, Iglesia I, et al. Can food parenting practices explain the association between parental education and children’s food intake? The Feel4Diabetes-study. Public Health Nutr. 2022;25:1-14. doi:10.1017/s1368980022000891. | Study design
267 | Flórez KR, Richardson AS, Ghosh-Dastidar MB, et al. Improved parental dietary quality is associated with children’s dietary intake through the home environment. Obes Sci Pract. 2017;3:75-82. doi:10.1002/osp4.81. | Study design; Intervention/exposure
268 | Folta SC, Anzman-Frasca S, Tsai M, et al. Snack It Up for Parents: Brief Videos and Tip Sheets for Promoting Vegetable Snacks to School-Aged Children. J Nutr Educ Behav. 2020;52:565-567. doi:10.1016/j.jneb.2019.12.003. | Study design; Outcome
269 | Fox MK, Pac S, Devaney B, et al. Feeding infants and toddlers study: What foods are infants and toddlers eating?. J Am Diet Assoc. 2004;104:s22-30. doi:10.1016/j.jada.2003.10.026. | Study design; Intervention/exposure
270 | Fox MK, Reidy K, Karwe V, et al. Average portions of foods commonly eaten by infants and toddlers in the United States. J Am Diet Assoc. 2006;106:S66-76. doi:10.1016/j.jada.2005.09.042. | Study design
271 | Frank GailC, Nguyen Rodriguez SelenaT, Bird Mara, et al. Primary Outcomes of a Healthy Lifestyle Intervention for Latino Families. Californian Journal of Health Promotion. 2020;18:29-38. doi:10.32398/cjhp.v18i1.2452. | Study design; Intervention/exposure
272 | French GM, Nicholson L, Skybo T, et al. An evaluation of mother-centered anticipatory guidance to reduce obesogenic infant feeding behaviors. Pediatrics. 2012;130:e507-17. doi:10.1542/peds.2011-3027. | Intervention/exposure
273 | French SA, Sherwood NE, JaKa MM, et al. Physical changes in the home environment to reduce television viewing and sugar-sweetened beverage consumption among 5- to 12-year-old children: a randomized pilot study. Pediatr Obes. 2016;11:e12-5. doi:10.1111/ijpo.12067. | Intervention/exposure
274 | Fries LR, Martin N, van der Horst K. Parent-child mealtime interactions associated with toddlers’ refusals of novel and familiar foods. Physiol Behav. 2017;176:93-100. doi:10.1016/j.physbeh.2017.03.001. | Study design; Outcome
275 | Fuemmeler BF, Stroo M, Lee CT, et al. Racial Differences in Obesity-Related Risk Factors Between 2-Year-Old Children Born of Overweight Mothers. J Pediatr Psychol. 2015;40:649-56. doi:10.1093/jpepsy/jsv023. | Study design
276 | Fuligni GL, Gonzalez CJ, Figueroa R. Adolescents’ proxy reports on obesity-related parenting practices: factorial validity and reliability across four behavioral domains. BMC Public Health. 2022;22:329. doi:10.1186/s12889-022-12745-5. | Study design
277 | Fulkerson JA, Friend S, Horning M, et al. Family Home Food Environment and Nutrition-Related Parent and Child Personal and Behavioral Outcomes of the Healthy Home Offerings via the Mealtime Environment (HOME) Plus Program: A Randomized Controlled Trial. J Acad Nutr Diet. 2018;118:240-251. doi:10.1016/j.jand.2017.04.006. | Age of some participants at I/E
278 | Fulkerson JA, Horning ML, Barr-Anderson DJ, et al. Universal childhood obesity prevention in a rural community: Study design, methods and baseline participant characteristics of the NU-HOME randomized controlled trial. Contemp Clin Trials. 2021;100:106160. doi:10.1016/j.cct.2020.106160. | Study design
279 | Fulkerson JA, Kubik MY, Story M, et al. Are there nutritional and other benefits associated with family meals among at-risk youth?. J Adolesc Health. 2009;45:389-95.doi:10.1016/j.jadohealth.2009.02.011. | Study design
280 | Fulkerson JA, Loth K, Bruening M, et al. Time 2 tlk 2nite: use of electronic media by adolescents during family meals and associations with demographic characteristics, family characteristics, and foods served. J Acad Nutr Diet. 2014;114:1053-1058. doi:10.1016/j.jand.2013.10.015. | Study design
281 | Fulkerson JA, Rydell S, Kubik MY, et al. Healthy Home Offerings via the Mealtime Environment (HOME): feasibility, acceptability, and outcomes of a pilot study. Obesity (Silver Spring). 2010;18 Suppl 1:S69-74. doi:10.1038/oby.2009.434. | INCLUDE; Outcome
282 | Fung SSW, Lam TH, Sun Y, et al. A cluster randomized controlled trial of more appreciation and less criticism in Hong Kong parents. J Fam Psychol. 2020;34:731-739. doi:10.1037/fam0000628. | Intervention/exposure; Outcome
283 | Gago C, Aftosmes-Tobio A, Beckerman-Hsu JP, et al. Evaluation of a cluster-randomized controlled trial: Communities for Healthy Living, family-centered obesity prevention program for Head Start parents and children. Int J Behav Nutr Phys Act. 2023;20:4. doi:10.1186/s12966-022-01400-2. | Intervention/exposure
284 | Galloway AT, Fiorito L, Lee Y, et al. Parental pressure, dietary patterns, and weight status among girls who are “picky eaters”. J Am Diet Assoc. 2005;105:541-8. doi:10.1016/j.jada.2005.01.029. | Study design
285 | Garcia AL, Athifa N, Hammond E, et al. Community-based cooking programme ‘Eat Better Feel Better’ can improve child and family eating behaviours in low socioeconomic groups. J Epidemiol Community Health. 2020;74:190-196. doi:10.1136/jech-2018- 211773. | Intervention/exposure
286 | Garipağaoğlu M, Sahip Y, Darendeliler F, et al. Family-based group treatment versus individual treatment in the management of childhood obesity: randomized, prospective clinical trial. Eur J Pediatr. 2009;168:1091-9. doi:10.1007/s00431-008-0894-8. | Intervention/exposure; Outcome
287 | Gasser CE, Mensah FK, Clifford SA, et al. Parental health behaviour predictors of childhood and adolescent dietary trajectories. Public Health Nutr. 2018;21:1874-1885. doi:10.1017/s1368980018000563. | Intervention/exposure; Outcome
288 | Gebremariam MK, Chinapaw MJ, Bringolf-Isler B, et al. Screen-based sedentary time: Association with soft drink consumption and the moderating effect of parental education in European children: The ENERGY study. PLoS One. 2017;12:e0171537. doi:10.1371/journal.pone.0171537. | Study design; Intervention/exposure
289 | Gebremariam MK, Henjum S, Terragni L, et al. Correlates of fruit, vegetable, soft drink, and snack intake among adolescents: the ESSENS study. Food Nutr Res. 2016;60:32512. doi:10.3402/fnr.v60.32512. | Study design
290 | Gedney Larissa. Family Mealtime. Today’s Dietitian. 2013;15:30-36. | Publication status
291 | Gerards SM, Dagnelie PC, Gubbels JS, et al. The effectiveness of lifestyle triple P in the Netherlands: a randomized controlled trial. PLoS One. 2015;10:e0122240. doi:10.1371/journal.pone.0122240. | Intervention/exposure
292 | Ghofranipour F, Hamzavi Zarghani N, Mohammadi E, et al. An internet-based educational intervention for mothers targeting preschoolers’ weight management promotion (PWMP): a pilot study. BMC Public Health. 2022;22:2220. doi:10.1186/s12889-022-14543-5. | Study design; Intervention/exposure
293 | Gholami M, Wiedemann A, Knoll N, et al. Mothers improve their daughters’ vegetable intake: a randomized controlled trial. Psychol Health Med. 2015;20:1-7. doi:10.1080/13548506.2014.902485. | Age of some participants at I/E
294 | Giannì ML, Bezze E, Colombo L, et al. Complementary Feeding Practices in a Cohort of Italian Late Preterm Infants. Nutrients. 2018;10(12):1861. Published 2018 Dec 2. doi:10.3390/nu10121861 | Intervention/exposure
295 | Gilbertson SL, Graves BA. Motivating parents to promote cardiovascular health in children. J Cardiovasc Nurs. 2015;30:E8-18. doi:10.1097/jcn.0000000000000126. | Study design; Intervention/exposure
296 | Gillman MW, Rifas-Shiman SL, Frazier AL, et al. Family dinner and diet quality among older children and adolescents. Arch Fam Med. 2000;9:235-40.doi:10.1001/archfami.9.3.235. | Study design
297 | Gittelsohn J, Toporoff EG, Story M, et al. Food Perceptions and Dietary Behavior of American-Indian Children, Their Caregivers, and Educators: Formative Assessment Findings from Pathways. J Nutr Educ. 2000;32:2-13. doi:10.1016/s0022-3182(00)70504- 8. | Study design; Intervention/exposure; Outcome
298 | Goldman RL, Radnitz CL, McGrath RE. The role of family variables in fruit and vegetable consumption in pre-school children. J Public Health Res. 2012;1:143-8. doi:10.4081/jphr.2012.e22. | Study design
299 | Golley RK, Hendrie GA. The impact of replacing regular-with reduced-fat dairy foods on children’s wider food intake: secondary analysis of a cluster RCT. Eur J Clin Nutr. 2012;66:1130-4. doi:10.1038/ejcn.2012.113. | Intervention/exposure
300 | Golley RK, Magarey AM, Daniels LA. Children’s food and activity patterns following a six-month child weight management program. Int J Pediatr Obes. 2011;6:409-14. doi:10.3109/17477166.2011.605894. | Intervention/exposure
301 | Golova N, Eskander J, Pho A, et al. Preventing the Early Introduction of Juice and Sugar-Sweetened Beverages in Infants’ Diets: A Randomized Controlled Trial. Clin Pediatr (Phila). 2023;62:276-287. doi:10.1177/00099228221119983. | Intervention/exposure; Outcome
302 | Gomes AI, Barros L, Pereira AI, et al. Effectiveness of a parental school-based intervention to improve young children’s eating patterns: a pilot study. Public Health Nutr. 2018;21:2485-2496. doi:10.1017/s1368980018000952. | Outcome
303 | Gomes AI, Pereira AI, Nogueira PC, Barros L. Development of a New Questionnaire to Assess Parental Perceived Barriers When Promoting Healthy Eating Habits in Young Children: First Findings. Nutrients. 2023;15(21):4672. Published 2023 Nov 4. doi:10.3390/nu15214672 | Study design
304 | Goodell Suzanne L, Pierce MichelleB, Amico Rivet K, et al. Parental Information, Motivation, and Behavioral Skills Correlate with Child Sweetened Beverage Consumption. Journal of Nutrition Education & Behavior. 2012;44:240-245. doi:10.1016/j.jneb.2010.07.012. | Study design
305 | Goodman LC, Roberts LT, Musher-Eizenman DR. Mindful feeding: A pathway between parenting style and child eating behaviors. Eat Behav. 2020;36:101335. doi:10.1016/j.eatbeh.2019.101335. | Study design; Outcome
306 | Granner ML, Evans AE. Variables associated with fruit and vegetable intake in adolescents. Am J Health Behav. 2011;35:591-602. doi:10.5993/ajhb.35.5.8. | Study design
307 | Granner ML, Sargent RG, Calderon KS, et al. Factors of fruit and vegetable intake by race, gender, and age among young adolescents. J Nutr Educ Behav. 2004;36:173-80. doi:10.1016/s1499-4046(06)60231-5. | Study design
308 | Gray HL, Buro AW, Sinha S. Associations Among Parents’ Eating Behaviors, Feeding Practices, and Children’s Eating Behaviors. Matern Child Health J. 2023;27:202-209. doi:10.1007/s10995-022-03572-6. | Study design
309 | Gregory JE, Paxton SJ, Brozovic AM. Maternal feeding practices predict fruit and vegetable consumption in young children. Results of a 12-month longitudinal study. Appetite. 2011;57:167-72. doi:10.1016/j.appet.2011.04.012. | Age of some participants at I/E
310 | Griauzde DH, Lumeng JC, Shah PE, et al. Lower Body Mass Index Z-Score Trajectory During Early Childhood After the Birth of a Younger Sibling. Acad Pediatr. 2019;19:51- 57. doi:10.1016/j.acap.2018.06.003. | Intervention/exposure; Outcome
311 | Gribble LS, Falciglia G, Davis AM, et al. A curriculum based on social learning theory emphasizing fruit exposure and positive parent child-feeding strategies: a pilot study. J Am Diet Assoc. 2003;103:100-3. doi:10.1053/jada.2003.50011. | Age of some participants at I/E
312 | Grimm GC, Harnack L, Story M. Factors associated with soft drink consumption in school-aged children. J Am Diet Assoc. 2004;104:1244-9. doi:10.1016/j.jada.2004.05.206. | Study design
313 | Groele B, Głąbska D, Gutkowska K, Guzek D. Mother’s Fruit Preferences and Consumption Support Similar Attitudes and Behaviors in Their Children. Int J Environ Res Public Health. 2018;15(12):2833. Published 2018 Dec 12. doi:10.3390/ijerph15122833 | Study design; Intervention/exposure
314 | Gross RS, Mendelsohn AL, Fierman AH, et al. Food insecurity and obesogenic maternal infant feeding styles and practices in low-income families. Pediatrics. 2012;130:254-61.doi:10.1542/peds.2011-3588. | Study design; Outcome
315 | Gross RS, Mendelsohn AL, Messito MJ. Additive effects of household food insecurity during pregnancy and infancy on maternal infant feeding styles and practices. Appetite. 2018;130:20-28. doi:10.1016/j.appet.2018.07.016. | Intervention/exposure; Age of some participants at I/E; Age at outcome
316 | Gross SM, Pollock ED, Braun B. Family influence: key to fruit and vegetable consumption among fourth- and fifth-grade students. J Nutr Educ Behav. 2010;42:235- 41. doi:10.1016/j.jneb.2009.05.007. | Study design
317 | Grutzmacher SK, Braunscheidel Duru E, Speirs KE, et al. Using text messages to engage low-income parents in school-based nutrition education. Journal of Hunger and Environmental Nutrition. 2018;13:335-339. doi:10.1080/19320248.2017.1364196. | Intervention/exposure; Outcome
318 | Gubbels JS, Gerards SM, Kremers SP. The association of parenting practices with toddlers’ dietary intake and BMI, and the moderating role of general parenting and child temperament. Public Health Nutr. 2020;23:2521-2529. doi:10.1017/s136898002000021x. | Study design
319 | Gubbels JS, Kremers SP, Goldbohm RA, et al. Energy balance-related behavioural patterns in 5-year-old children and the longitudinal association with weight status development in early childhood. Public Health Nutr. 2012;15:1402-10. doi:10.1017/s1368980011003089. | Intervention/exposure
320 | Gubbels JS, Kremers SP, Stafleu A, et al. Diet-related restrictive parenting practices. Impact on dietary intake of 2-year-old children and interactions with child characteristics. Appetite. 2009;52:423-9. doi:10.1016/j.appet.2008.12.002. | Study design
321 | Gunther C, Rogers C, Holloman C, et al. Child diet and health outcomes of the simple suppers program: a 10-week, 2-group quasi-experimental family meals trial. BMC Public Health. 2019;19:1657. doi:10.1186/s12889-019-7930-7. | Age of some participants at I/E
322 | Haddad J, Ullah S, Bell L, et al. The Influence of Home and School Environments on Children’s Diet and Physical Activity, and Body Mass Index: A Structural Equation Modelling Approach. Matern Child Health J. 2018;22:364-375. doi:10.1007/s10995-017- 2386-9. | Study design
323 | Haddad J, Vasiloglou MF, Scheidegger-Balmer F, et al. Home-based cooking intervention with a smartphone app to improve eating behaviors in children aged 7- 9 years: a feasibility study. Discov Soc Sci Health. 2023;3:13. doi:10.1007/s44155-023- 00042-4. | Intervention/exposure; Outcome
324 | Haerens L, De Bourdeaudhuij I, Maes L, et al. The effects of a middle-school healthy eating intervention on adolescents’ fat and fruit intake and soft drinks consumption. Public Health Nutr. 2007;10:443-9. doi:10.1017/s1368980007219652. | Intervention/exposure
325 | Haerens L, Deforche B, Maes L, et al. Evaluation of a 2-year physical activity and healthy eating intervention in middle school children. Health Educ Res. 2006;21:911-21. doi:10.1093/her/cyl115. | Intervention/exposure
326 | Haines J, Douglas S, Mirotta JA, et al. Guelph Family Health Study: pilot study of a home-based obesity prevention intervention. Can J Public Health. 2018;109:549-560. doi:10.17269/s41997-018-0072-3. | Intervention/exposure
327 | Haire-Joshu D, Brownson RC, Nanney MS, et al. Improving dietary behavior in African Americans: The Parents As Teachers High 5, Low Fat Program. Preventive Medicine. 2003;36:684-691. doi:10.1016/S0091-7435(03)00053-7. | Intervention/exposure; Outcome; Age of some participants at I/E
328 | Haire-Joshu D, Schwarz C, Jacob R, et al. Raising Well at Home: a pre-post feasibility study of a lifestyle intervention for caregivers and their child with obesity. Pilot Feasibility Stud. 2020;6:149. doi:10.1186/s40814-020-00692-0. | Study design; Intervention/exposure
329 | Hammersley ML, Jones RA, Okely AD. Relationships Between the Home Learning Environment, Weight Status, and Dietary Intake: Results From a Cross-Sectional Study of Preschool-Aged Children in New South Wales, Australia. J Prim Prev. 2021;42:239- 256. doi:10.1007/s10935-021-00628-1. | Study design
330 | Hammersley ML, Okely AD, Batterham MJ, et al. Investigating the mediators and moderators of child body mass index change in the Time2bHealthy childhood obesity prevention program for parents of preschool-aged children. Public Health. 2019;173:50-57. doi:10.1016/j.puhe.2019.04.017. | Intervention/exposure; Outcome
331 | Hammersley ML, Wyse RJ, Jones RA, et al. Translation of Two Healthy Eating and Active Living Support Programs for Parents of 2-6-Year-Old Children: Outcomes of the ‘Time for Healthy Habits’ Parallel Partially Randomised Preference Trial. Nutrients. 2021;13(10):3348. Published 2021 Sep 24. doi:10.3390/nu13103348 | Intervention/exposure
332 | Hammons AJ, Hannon BA, Teran-Garcia M, et al. Effects of Culturally Tailored Nutrition Education on Dietary Quality of Hispanic Mothers: A Randomized Control Trial. J Nutr Educ Behav. 2019;51:1168-1176. doi:10.1016/j.jneb.2019.06.017. | Intervention/exposure; Outcome
333 | Hammons AJ, Wiley AR, Fiese BH, et al. Six-week Latino family prevention pilot program effectively promotes healthy behaviors and reduces obesogenic behaviors. J Nutr Educ Behav. 2013;45:745-50. doi:10.1016/j.jneb.2013.01.023. | Study design; Intervention/exposure
334 | Hanson NI, Neumark-Sztainer D, Eisenberg ME, et al. Associations between parental report of the home food environment and adolescent intakes of fruits, vegetables and dairy foods. Public Health Nutr. 2005;8:77-85. doi:10.1079/phn2005661. | Study design
335 | Harbec MJ, Pagani LS. Associations Between Early Family Meal Environment Quality and Later Well-Being in School-Age Children. J Dev Behav Pediatr. 2018;39:136-143. doi:10.1097/dbp.0000000000000520. | Age of some participants at I/E
336 | Hardt J, Canfell OJ, Walker JL, et al. Healthier Together: Implementation and evaluation of a co-designed, culturally tailored childhood obesity community prevention program for Māori and Pacific Islander children and families. Health Promot J Austr. 2024;35(3):744- 759. doi:10.1002/hpja.803 | Study design
337 | Hare ME, Coday M, Williams NA, et al. Methods and baseline characteristics of a randomized trial treating early childhood obesity: the Positive Lifestyles for Active Youngsters (Team PLAY) trial. Contemp Clin Trials. 2012;33:534-49. doi:10.1016/j.cct.2012.02.003. | Study design; Outcome
338 | Harrington KF, Franklin FA, Davies SL, et al. Implementation of a family intervention to increase fruit and vegetable intake: the Hi5+ experience. Health Promot Pract. 2005;6:180-9. doi:10.1177/1524839904263681. | Intervention/exposure; Outcome
339 | Harris TS, Ramsey M. Paternal modeling, household availability, and paternal intake as predictors of fruit, vegetable, and sweetened beverage consumption among African American children. Appetite. 2015;85:171-7. doi:10.1016/j.appet.2014.11.008. | Study design
340 | Harrison M, Brodribb W, Davies PSW, et al. Impact of Maternal Infant Weight Perception on Infant Feeding and Dietary Intake. Matern Child Health J. 2018;22:1135-1145. doi:10.1007/s10995-018-2498-x. | Study design
341 | Harrison Michelle, Brodribb Wendy, Davies PeterSW, et al. Relationships between parental feeding practices, infant weight concern, infant dietary behaviour and body weight: Findings from the Feeding A Baby (FAB) Study. Obesity Research & Clinical Practice. 2019;13:86-86. doi:10.1016/j.orcp.2016.10.238. | Publication status
342 | Hart LM, Damiano SR, Li-Wai-Suen CSN, et al. Confident body, confident child: Evaluation of a universal parenting resource promoting healthy body image and eating patterns in early childhood-6- and 12-month outcomes from a randomized controlled trial. Int J Eat Disord. 2019;52:121-131. doi:10.1002/eat.22992. | Outcome
343 | Hart LM, Damiano SR, Paxton SJ. Confident body, confident child: A randomized controlled trial evaluation of a parenting resource for promoting healthy body image and eating patterns in 2- to 6-year old children. Int J Eat Disord. 2016;49:458-72. doi:10.1002/eat.22494. | Outcome
344 | Hashemian M, Abdolkarimi M, Nasirzadeh M. Family and school-based educational intervention on fruits and vegetable consumption of female students: Application of social cognitive theory. J Educ Health Promot. 2022;11:55. doi:10.4103/jehp.jehp_47_21. | Intervention/exposure
345 | Haslam A, Love C, Taniguchi T, et al. Development and Implementation of a Hybrid Online and In-Person Food Sovereignty and Nutrition Education Curriculum for Native American Parents: The FRESH Study. Health Educ Behav. 2023;50:430-440. doi:10.1177/10901981211067168. | Study design
346 | Haß J, Hartmann M. What determines the fruit and vegetables intake of primary school children? - An analysis of personal and social determinants. Appetite. 2018;120:82-91.doi:10.1016/j.appet.2017.08.017. | Study design
347 | Haszard JJ, Skidmore PM, Williams SM, et al. Associations between parental feeding practices, problem food behaviours and dietary intake in New Zealand overweight children aged 4-8 years. Public Health Nutr. 2015;18:1036-43. doi:10.1017/s1368980014001256. | Study design
348 | Haszard JJ, Williams SM, Dawson AM, et al. Factor analysis of the Comprehensive Feeding Practices Questionnaire in a large sample of children. Appetite. 2013;62:110-8. doi:10.1016/j.appet.2012.11.017. | Study design; Outcome
349 | Haughton CF, Waring ME, Wang ML, et al. Home Matters: Adolescents Drink More Sugar-Sweetened Beverages When Available at Home. J Pediatr. 2018;202:121-128. doi:10.1016/j.jpeds.2018.06.046. | Study design
350 | He L, Zhai Y, Engelgau M, et al. Association of children’s eating behaviors with parental education, and teachers’ health awareness, attitudes and behaviors: a national school-based survey in China. Eur J Public Health. 2014;24:880-7. doi:10.1093/eurpub/ckt177. | Study design
351 | Heim S, Bauer KW, Stang J, et al. Can a community-based intervention improve the home food environment? parental perspectives of the influence of the delicious and nutritious garden. J Nutr Educ Behav. 2011;43:130-4. doi:10.1016/j.jneb.2010.01.003. | Study design; Intervention/exposure
352 | Helle C, Hillesund ER, Wills AK, et al. Evaluation of an eHealth intervention aiming to promote healthy food habits from infancy -the Norwegian randomized controlled trial Early Food for Future Health. Int J Behav Nutr Phys Act. 2019;16:1. doi:10.1186/s12966- 018-0763-4. | Age of some participants at I/E
353 | Helle C, Hillesund ER, Wills AK, et al. Examining the effects of an eHealth intervention from infant age 6 to 12 months on child eating behaviors and maternal feeding practices one year after cessation: The Norwegian randomized controlled trial Early Food for Future Health. PLoS One. 2019;14:e0220437. doi:10.1371/journal.pone.0220437. | Age of some participants at I/E
354 | Helsel BC, Liang J, Williams JE, et al. Family and Friend Influences on Fruit and Vegetable Intake in Elementary Aged Children. J Community Health. 2019;44:932-940. doi:10.1007/s10900-019-00640-x. | Intervention/exposure
355 | Hendrie GA, Coveney J, Cox DN. Defining the complexity of childhood obesity and related behaviours within the family environment using structural equation modelling. Public Health Nutr. 2012;15:48-57. doi:10.1017/s1368980011001832. | Study design
356 | Hendy H, Harclerode W, Williams KE. The Parent Mealtime Action Scale revised (PMAS-R): Psychometric characteristics and associations with variables of clinical interest. Appetite. 2016;105:283-90. doi:10.1016/j.appet.2016.05.025. | Study design
357 | Hendy HM, Williams KE, Camise TS, et al. The Parent Mealtime Action Scale (PMAS). Development and association with children’s diet and weight. Appetite. 2009;52:328-39. doi:10.1016/j.appet.2008.11.003. | Study design
358 | Herawati HD, Putri AG, Purnamasari Y, et al. Nutrition Education using Booklet Media with and Without Counseling and the Association with Home Food Availability and Parent Feeding Practices in Preschool Children. Open Access Macedonian Journal of Medical Sciences. 2022;10:160-166. doi:10.3889/oamjms.2022.9490. | Outcome
359 | Hernandez E, Hohman EE, Ferrante MJ, Anzman-Frasca S, Paul IM, Savage JS. Toddler dietary patterns from the INSIGHT randomized clinical trial comparing responsive parenting versus control: A latent class analysis. Obesity (Silver Spring). 2024;32(1):141-149. doi:10.1002/oby.23900. | Age of some participants at I/E
360 | Hesketh KD, Salmon J, McNaughton SA, et al. Long-term outcomes (2 and 3.5 years post-intervention) of the INFANT early childhood intervention to improve health behaviors and reduce obesity: cluster randomised controlled trial follow-up. Int J Behav Nutr Phys Act. 2020;17:95. doi:10.1186/s12966-020-00994-9. | Age of some participants at I/E
361 | Hillesund ER, Sagedal LR, Bere E, et al. Family meal participation is associated with dietary intake among 12-month-olds in Southern Norway. BMC Pediatr. 2021;21:128. doi:10.1186/s12887-021-02591-6. | Study design; Intervention/exposure
362 | Hilmers Angela, Cullen KW, Moore Carolyn, et al. Exploring the Association Between Household Food Insecurity, Parental Self-Efficacy, and Fruit and Vegetable Parenting Practices Among Parents of 5- to 8-Year-Old Overweight Children. Journal of Applied Research on Children. 2012;3:1-15. doi:10.58464/2155-5834.1055. | Study design
363 | Hilsen M, van Stralen MM, Klepp KI, et al. Changes in 10-12 year old’s fruit and vegetable intake in Norway from 2001 to 2008 in relation to gender and socioeconomic status - a comparison of two cross-sectional groups. Int J Behav Nutr Phys Act. 2011;8:108. doi:10.1186/1479-5868-8-108. | Study design
364 | Hoerr SL, Hughes SO, Fisher JO, et al. Associations among parental feeding styles and children’s food intake in families with limited incomes. Int J Behav Nutr Phys Act. 2009;6:55. doi:10.1186/1479-5868-6-55. | Study design
365 | Hoffhines H, Whaley KD, Blackett PR, et al. Early childhood nutrition in an American Indian community: educational strategy for obesity prevention. J Okla State Med Assoc. 2014;107:55-9. | Study design; Intervention/exposure
366 | Hoffman ER, Bentley ME, Hamer RM, et al. A comparison of infant and toddler feeding practices of mothers with and without histories of eating disorders. Matern Child Nutr. 2014;10:360-72. doi:10.1111/j.1740-8709.2012.00429.x. | Study design; Comparator
367 | Hoffmann DA, Marx JM, Kiefner-Burmeister A, et al. Influence of maternal feeding goals and practices on children’s eating behaviors. Appetite. 2016;107:21-27. doi:10.1016/j.appet.2016.07.014. | Study design
368 | Hohman EE, Paul IM, Birch LL, et al. INSIGHT responsive parenting intervention is associated with healthier patterns of dietary exposures in infants. Obesity (Silver Spring). 2017;25:185-191. doi:10.1002/oby.21705. | Outcome; Age of some participants at I/E
369 | Hohman EE, Savage JS, Birch LL, et al. The Intervention Nurses Start Infants Growing on Healthy Trajectories (INSIGHT) Responsive Parenting Intervention for Firstborns Affects Dietary Intake of Secondborn Infants. J Nutr. 2020;150:2139-2146. doi:10.1093/jn/nxaa135. | Age of some participants at I/E
370 | Holley CE, Farrow C, Haycraft E. Investigating the role of parent and child characteristics in healthy eating intervention outcomes. Appetite. 2016;105:291-7. doi:10.1016/j.appet.2016.05.038. | Outcome
371 | Holley CE, Haycraft E, Farrow C. Predicting children’s fussiness with vegetables: The role of feeding practices. Matern Child Nutr. 2018;14(1):e12442. doi:10.1111/mcn.12442 | Study design
372 | Holley CE, Haycraft E, Farrow C. ‘Why don’t you try it again?’ A comparison of parent led, home based interventions aimed at increasing children’s consumption of a disliked vegetable. Appetite. 2015;87:215-22. doi:10.1016/j.appet.2014.12.216. | Intervention/exposure; Outcome
373 | Holmes JF, St Laurent CW, Spencer RMC. Unhealthy Diet Is Associated With Poor Sleep in Preschool-Aged Children. J Genet Psychol. 2021;182:289-303. doi:10.1080/00221325.2021.1905598. | Study design
374 | Holubcikova J, Kolarcik P, Madarasova Geckova A, et al. Lack of parental rule-setting on eating is associated with a wide range of adolescent unhealthy eating behaviour both for boys and girls. BMC Public Health. 2016;16:359. doi:10.1186/s12889-016-3002-4. | Study design
375 | Horning ML, Friend S, Lee J, et al. Family Characteristics Associated with Preparing and Eating More Family Evening Meals at Home. J Acad Nutr Diet. 2022;122:121-128. doi:10.1016/j.jand.2021.07.002. | Study design
376 | Horodynski MA, Hoerr S, Coleman G. Nutrition education aimed at toddlers: a pilot program for rural, low-income families. Fam Community Health. 2004;27:103-13. doi:10.1097/00003727-200404000-00003. | Intervention/exposure; Outcome
377 | Horodynski MA, Stommel M, Brophy-Herb HE, et al. Mealtime television viewing and dietary quality in low-income African American and Caucasian mother-toddler dyads. Matern Child Health J. 2010;14:548-56. doi:10.1007/s10995-009-0501-2. | Study design
378 | Horton LA, Parada H, Slymen DJ, et al. Targeting children’s dietary behaviors in a family intervention: ‘Entre familia: reflejos de salud’. Salud Publica Mex. 2013;55 Suppl 3:397- 405. | Intervention/exposure
379 | Housely A, Branscum P, Cheney M, et al. Predicting parental monitoring behaviours for sugar-sweetened beverages in parents of school-aged children: An application of the Integrative Behavioural Model. Health Education Journal. 2016;75:577-588. doi:10.1177/0017896915607918. | Study design
380 | Hruska V, Shivappa N, Hébert JR, Duncan AM, Haines J, Ma DWL. Associations between Family-Based Stress and Dietary Inflammatory Potential among Families with Preschool-Aged Children. Nutrients. 2021;13(5):1464. Published 2021 Apr 26.doi:10.3390/nu13051464 | Study design; Intervention/exposure
381 | Hughes SO, Patrick H, Power TG, et al. The impact of child care providers’ feeding on children’s food consumption. J Dev Behav Pediatr. 2007;28:100-7. doi:10.1097/01.DBP.0000267561.34199.a9. | Study design
382 | Hughes SO, Power TG, Beck A, et al. Short-Term Effects of an Obesity Prevention Program Among Low-Income Hispanic Families With Preschoolers. J Nutr Educ Behav. 2020;52:224-239. doi:10.1016/j.jneb.2019.12.001. | Outcome
383 | Hughes SO, Power TG, Beck AD, et al. Twelve-Month Efficacy of an Obesity Prevention Program Targeting Hispanic Families With Preschoolers From Low-Income Backgrounds. J Nutr Educ Behav. 2021;53:677-690. doi:10.1016/j.jneb.2021.04.460. | Study design; Outcome
384 | Humenikova L, Gates GE. Social and physical environmental factors and child overweight in a sample of American and Czech school-aged children: a pilot study. J Nutr Educ Behav. 2008;40:251-7. doi:10.1016/j.jneb.2007.06.008. | Study design; Outcome
385 | Isasi CR, Hua S, Jung M, et al. The Association of Parental/Caregiver Chronic Stress with Youth Obesity: Findings from the Study of Latino Youth and the Hispanic Community Health Study/Study of Latinos Sociocultural Ancillary Study. Child Obes. 2017;13:251-258. doi:10.1089/chi.2016.0205. | Intervention/exposure; Outcome
386 | Izumi BT, Eckhardt CL, Wilson DP, et al. A Cooking Intervention to Increase Vegetable Consumption by Parents With Children Enrolled in an Early Head Start Home Visiting Program: A Pilot Study in Portland, Oregon, 2013-2014. Prev Chronic Dis. 2016;13:E174. doi:10.5888/pcd13.160259. | Study design; Intervention/exposure
387 | Jackson JA, Smit E, Manore MM, et al. The Family-Home Nutrition Environment and Dietary Intake in Rural Children. Nutrients. 2015;7:9707-20. doi:10.3390/nu7125495. | Study design
388 | Jackson K, Jansen E, Mallan KM. Examining child intake frequency, mothers’ own liking and child early exposure as potential predictors of child liking for restricted foods and drinks at 5 years old. Public Health Nutr. 2020;23:2355-2364. doi:10.1017/s1368980020000312. | Intervention/exposure
389 | Jacobi C, Agras WS, Bryson S, et al. Behavioral validation, precursors, and concomitants of picky eating in childhood. J Am Acad Child Adolesc Psychiatry. 2003;42:76-84. doi:10.1097/00004583-200301000-00013. | Outcome
390 | Jaeger MargaretM, Vieth Grace, Rothman AlexanderJ, et al. Parents’ use of intentional modeling and social control to influence their adolescent’s health behavior: Findings from the FLASHE study. Journal of Social & Personal Relationships. 2021;38:2722-2741. doi:10.1177/02654075211020136. | Study design; Outcome
391 | Jager Gerry, Mueller Carina, de Graaf Cees, et al. Effects of parental restriction on intake of sugary foods and beverages and sweetness preferences in 4-7-year-old children. Appetite. 2022;179:N.PAG-N.PAG. doi:10.1016/j.appet.2022.106221. | Publication status
392 | James KS, Connelly CD, Gracia L, et al. Ways to Enhance Children’s Activity and Nutrition (WE CAN) - a pilot project with Latina mothers. J Spec Pediatr Nurs. 2010;15:292-300. doi:10.1111/j.1744-6155.2010.00252.x. | Study design; Outcome
393 | Jang M, Brandon D, Vorderstrasse A. Relationships Among Parental Psychological Distress, Parental Feeding Practices, Child Diet, and Child Body Mass Index. Nurs Res. 2019;68:296-306. doi:10.1097/nnr.0000000000000344. | Study design
394 | Jang M, Brown R, Vang PY. The Relationships Between Parental Stress, Home Food Environment, and Child Diet Patterns in Families of Preschool Children. Am J Health Promot. 2021;35:131-139. doi:10.1177/0890117120929541. | Study design
395 | Jansen E, Mulkens S, Emond Y, et al. From the Garden of Eden to the land of plenty Restriction of fruit and sweets intake leads to increased fruit and sweets consumption in children. Appetite. 2008;51:570-575. doi:10.1016/j.appet.2008.04.012. | Intervention/exposure; Outcome
396 | Jansen E, Mulkens S, Jansen A. How to promote fruit consumption in children. Visual appeal versus restriction. Appetite. 2010;54:599-602. doi:10.1016/j.appet.2010.02.012. | Intervention/exposure; Outcome
397 | Jarman M, Ogden J, Inskip H, et al. How do mothers manage their preschool children’s eating habits and does this change as children grow older? A longitudinal analysis. Appetite. 2015;95:466-74. doi:10.1016/j.appet.2015.08.008. | Outcome
398 | Jennings KM, Loth KA, Tate AD, et al. Application of latent profile analysis to define subgroups of parenting styles and food parenting practices. Appetite. 2019;139:8-18.doi:10.1016/j.appet.2019.04.001. | Study design
399 | Jessa J, Hozyasz KK. Assessing eating habits of children admitted to pediatric ward and nutrition knowledge of their parents – preliminary study. Pediatria Polska. 2016;91:208- 213. doi:10.1016/j.pepo.2016.02.005. | Intervention/exposure; Publication language
400 | Jia P, Li M, Xue H, et al. School environment and policies, child eating behavior and overweight/obesity in urban China: the childhood obesity study in China megacities. Int J Obes (Lond). 2017;41:813-819. doi:10.1038/ijo.2017.2. | Study design; Intervention/exposure; Country
401 | Johansen C, Reynolds KD, Xie B, et al. An Examination of Family Variables as Mediators of the Association of Acculturation With Sugar-Sweetened Beverage Consumption Among Latinx Adolescents. Fam Community Health. 2020;43:287-295. doi:10.1097/fch.0000000000000278. | Study design
402 | Johnson L, van Jaarsveld CH, Wardle J. Individual and family environment correlates differ for consumption of core and non-core foods in children. Br J Nutr. 2011;105:950-9. doi:10.1017/s0007114510004484. | Study design
403 | Joo J, Kim J, Kim DY, et al. Relationship in Quality of Diet, Food Habit and Feeding Practice in Children with Pervasive Developmental Disorder and Their Caregiver. Clin Nutr Res. 2019;8:91-100. doi:10.7762/cnr.2019.8.2.91. | Study design; Health status
404 | Jordan AA, Appugliese DP, Miller AL, et al. Maternal prompting types and child vegetable intake: Exploring the moderating role of picky eating. Appetite. 2020;146:104518. doi:10.1016/j.appet.2019.104518. | Study design
405 | Kähkönen K, Sandell M, Rönkä A, Hujo M, Nuutinen O. Children’s Fruit and Vegetable Preferences Are Associated with Their Mothers’ and Fathers’ Preferences. Foods. 2021;10(2):261. Published 2021 Jan 27. doi:10.3390/foods10020261 | Study design
406 | Kaiser LL, Aguilera AL, Horowitz M, et al. Correlates of food patterns in young Latino children at high risk of obesity. Public Health Nutr. 2015;18:3042-50. doi:10.1017/s1368980014003309. | Study design
407 | Karanja N, Lutz T, Ritenbaugh C, et al. The TOTS community intervention to prevent overweight in American Indian toddlers beginning at birth: a feasibility and efficacy study. Journal of community health. 2010;35:667-675. doi:10.1007/s10900-010-9270-5. | Intervention/exposure; Outcome
408 | Kasman M, Hammond RA, Purcell R, et al. An agent-based model of child sugar-sweetened beverage consumption: implications for policies and practices. Am J Clin Nutr. 2022;116:1019-1029. doi:10.1093/ajcn/nqac194. | Study design
409 | Kasparian M, Mann G, Serrano EL, et al. Parenting practices toward food and children’s behavior: Eating away from home versus at home. Appetite. 2017;114:194-199. doi:10.1016/j.appet.2017.03.045. | Study design; Intervention/exposure; Outcome
410 | Kasper N, Mandell C, Ball S, et al. The Healthy Meal Index: A tool for measuring the healthfulness of meals served to children. Appetite. 2016;103:54-63. doi:10.1016/j.appet.2016.02.160. | Study design; Intervention/exposure
411 | Kaufman-Shriqui V, Fraser D, Friger M, et al. Effect of a School-Based Intervention on Nutritional Knowledge and Habits of Low-Socioeconomic School Children in Israel: A Cluster-Randomized Controlled Trial. Nutrients. 2016;8:234. doi:10.3390/nu8040234. | Intervention/exposure
412 | Kegler MC, Bundy Ł T, Hartman T, et al. Promoting Healthier Home Food Environments Through 2-1-1: A Pilot and Feasibility Study. Fam Community Health. 2020;43:276-286. doi:10.1097/fch.0000000000000275. | Outcome; Age of some participants at I/E
413 | Kehm R, Hearst MO, Sherman S, et al. The FAV-S Pilot Study. Health Educ Behav. 2017;44:52-58. doi:10.1177/1090198116646367. | Intervention/exposure
414 | Keita AD, Risica PM, Drenner KL, et al. Feasibility and acceptability of an early childhood obesity prevention intervention: results from the healthy homes, healthy families pilot study. J Obes. 2014;2014:378501. doi:10.1155/2014/378501. | Study design
415 | Kerver JM, Brophy-Herb HE, Sturza J, et al. Supporting family meal frequency: Screening Phase results from the Simply Dinner Study. Appetite. 2022;174:106009. doi:10.1016/j.appet.2022.106009. | Intervention/exposure
416 | Keskitalo K, Silventoinen K, Tuorila H, et al. Genetic and environmental contributions to food use patterns of young adult twins. Physiol Behav. 2008;93:235-42. doi:10.1016/j.physbeh.2007.08.025. | Study design; Intervention/exposure
417 | Kiefner-Burmeister AE, Hoffmann DA, Meers MR, et al. Food consumption by young children: a function of parental feeding goals and practices. Appetite. 2014;74:6-11.doi:10.1016/j.appet.2013.11.011. | Study design
418 | Kilaru A, Griffiths PL, Ganapathy S, et al. Community-based nutrition education for improving infant growth in rural Karnataka. Indian Pediatrics. 2005;42:425-432. | Country
419 | Kininmonth AR, Schrempft S, Smith A, et al. Associations between the home environment and childhood weight change: a cross-lagged panel analysis. Int J Obes (Lond). 2022;46:1678-1685. doi:10.1038/s41366-022-01170-8. | Study design; Intervention/exposure
420 | Klerks M, Roman S, Bernal MJ, Haro-Vicente JF, Sanchez-Siles LM. Complementary Feeding Practices and Parental Pressure to Eat among Spanish Infants and Toddlers: A Cross-Sectional Study. Int J Environ Res Public Health. 2021;18(4):1982. Published 2021 Feb 18. doi:10.3390/ijerph18041982 | Study design
421 | Klingberg S, Ludvigsson J, Brekke HK. Introduction of complementary foods in Sweden and impact of maternal education on feeding practices. Public Health Nutr. 2017;20(6):1054-1062. doi:10.1017/S1368980016003104 | Intervention/exposure
422 | Knobl V, Dallacker M, Hertwig R, et al. Happy and healthy: How family mealtime routines relate to child nutritional health. Appetite. 2022;171:105939. doi:10.1016/j.appet.2022.105939. | Study design
423 | Knowlden AP, Conrad E. Two-Year Outcomes of the Enabling Mothers to Prevent Pediatric Obesity Through Web-Based Education and Reciprocal Determinism (EMPOWER) Randomized Control Trial. Health Educ Behav. 2018;45:262-276. doi:10.1177/1090198117732604. | Intervention/exposure
424 | Knowlden AP, Sharma M, Cottrell RR, et al. Impact evaluation of Enabling Mothers to Prevent Pediatric Obesity through Web-Based Education and Reciprocal Determinism (EMPOWER) Randomized Control Trial. Health Educ Behav. 2015;42:171-84. doi:10.1177/1090198114547816. | Intervention/exposure
425 | Knowlden AP, Sharma M. Social cognitive maternal-mediated nutritional correlates of childhood obesity. Int Q Community Health Educ. 2015;35:177-91. doi:10.1177/0272684x15569678. | Study design
426 | Kobel S, Wirt T, Schreiber A, et al. Intervention effects of a school-based health promotion programme on obesity related behavioural outcomes. J Obes. 2014;2014:476230. doi:10.1155/2014/476230. | Intervention/exposure
427 | Kołłątaj W, Sygit K, Sygit M, Karwat ID, Kołłątaj B. Eating habits of children and adolescents from rural regions depending on gender, education, and economic status of parents. Ann Agric Environ Med. 2011;18(2):393-397. | Study design; Intervention/exposure
428 | Kontochristopoulou AM, Karatzi K, Karaglani E, et al. Parental practices and children’s lifestyle correlates of childhood overweight/obesity in Europe: The Feel4Diabetes study. J Hum Nutr Diet. 2024;37(1):31-46. doi:10.1111/jhn.13229 | Study design
429 | Korn AR, Economos CD, Hammond RA, et al. Associations of mothers’ source of feeding information with longitudinal trajectories of sugar-sweetened beverage intake, 100% juice intake and adiposity in early childhood. Pediatr Obes. 2021;16:e12746. doi:10.1111/ijpo.12746. | Intervention/exposure
430 | Kovács E, Siani A, Konstabel K, et al. Adherence to the obesity-related lifestyle intervention targets in the IDEFICS study. Int J Obes (Lond). 2014;38 Suppl 2:S144-51. doi:10.1038/ijo.2014.145. | Intervention/exposure
431 | Kral TVE, Chittams J, Moore RH. Relationship between food insecurity, child weight status, and parent-reported child eating and snacking behaviors. J Spec Pediatr Nurs. 2017;22(2):10.1111/jspn.12177. doi:10.1111/jspn.12177 | Study design; Outcome
432 | Kral TVE, O’Malley L, Johnson K, et al. Effects of a mobile health nutrition intervention on dietary intake in children who have autism spectrum disorder. Front Pediatr. 2023;11:1100436. doi:10.3389/fped.2023.1100436. | Intervention/exposure; Health status
433 | Kratt P, Reynolds K, Shewchuk R. The role of availability as a moderator of family fruit and vegetable consumption. Health Educ Behav. 2000;27:471-82. doi:10.1177/109019810002700409. | Study design
434 | Kremers SP, Brug J, de Vries H, et al. Parenting style and adolescent fruit consumption. Appetite. 2003;41:43-50. doi:10.1016/s0195-6663(03)00038-2. | Study design; Intervention/exposure
435 | Kremer-Sadlik T, Morgenstern A, Peters C, et al. Eating fruits and vegetables: An ethnographic study of American and French family dinners. Appetite. 2015;89:84-92.doi:10.1016/j.appet.2015.01.012. | Study design
436 | Kremer-Sadlik T, Morgenstern A. The reflective eater: Socializing French children to eating fruits and vegetables. Appetite. 2022;172:105954. doi:10.1016/j.appet.2022.105954. | Study design
437 | Kristiansen AL, Bjelland M, Himberg-Sundet A, et al. Associations between physical home environmental factors and vegetable consumption among Norwegian 3-5-year-olds: the BRA-study. Public Health Nutr. 2017;20:1173-1183. doi:10.1017/s1368980016003396. | Study design
438 | Kristiansen AL, Bjelland M, Himberg-Sundet A, et al. Associations between sociocultural home environmental factors and vegetable consumption among Norwegian 3-5-year olds: BRA-study. Appetite. 2017;117:310-320. doi:10.1016/j.appet.2017.06.031. | Study design
439 | Kristiansen AL, Bjelland M, Himberg-Sundet A, et al. Effects of a cluster randomized controlled kindergarten-based intervention trial on vegetable consumption among Norwegian 3-5-year-olds: the BRA-study. BMC Public Health. 2019;19:1098. doi:10.1186/s12889-019-7436-3. | Intervention/exposure
440 | Kristiansen H, Júlíusson PB, Eide GE, et al. TV viewing and obesity among Norwegian children: the importance of parental education. Acta Paediatr. 2013;102:199-205. doi:10.1111/apa.12066. | Study design
441 | Kristjansdottir AG, Johannsson E, Thorsdottir I. Effects of a school-based intervention on adherence of 7-9-year-olds to food-based dietary guidelines and intake of nutrients. Public Health Nutr. 2010;13:1151-61. doi:10.1017/s1368980010000716. | Study design; Intervention/exposure
442 | Krølner R, Due P, Rasmussen M, et al. Does school environment affect 11-year-olds’ fruit and vegetable intake in Denmark?. Soc Sci Med. 2009;68:1416-24. doi:10.1016/j.socscimed.2009.01.022. | Study design; Intervention/exposure
443 | Kueppers J, Stein KF, Groth S, et al. Maternal and child dietary intake: The role of maternal healthy-eater self-schema. Appetite. 2018;125:527-536. doi:10.1016/j.appet.2018.01.014. | Study design
444 | Kuhl ES, Clifford LM, Bandstra NF, et al. Examination of the association between lifestyle behavior changes and weight outcomes in preschoolers receiving treatment for obesity. Health Psychol. 2014;33:95-8. doi:10.1037/a0032741. | Intervention/exposure
445 | Lacy KE, Spence AC, McNaughton SA, et al. Home environment predictors of vegetable and fruit intakes among Australian children aged 18 months. Appetite. 2019;139:95-104. doi:10.1016/j.appet.2019.04.009. | Age of some participants at I/E
446 | Lagström H, Seppänen R, Jokinen E, et al. The impact of child-targeted dietary counseling of parents on food (milk) preferences of preschool-aged children in the STRIP project. Scandinavian Journal of Nutrition/Naringsforskning. 2001;45:51-56. | Intervention/exposure; Outcome
447 | Lambrinou CP, van Stralen MM, Androutsos O, et al. Mediators of the effectiveness of a kindergarten-based, family-involved intervention on pre-schoolers’ snacking behaviour: the ToyBox-study. Public Health Nutr. 2019;22:157-163. doi:10.1017/s1368980018002653. | Intervention/exposure; Outcome
448 | Lande B, Andersen LF, Baerug A, et al. Infant feeding practices and associated factors in the first six months of life: the Norwegian infant nutrition survey. Acta Paediatr. 2003;92:152-61. doi:10.1111/j.1651-2227.2003.tb00519.x. | Study design
449 | Landry MJ, Burgermaster M, van den Berg AE, et al. Barriers to Preparing and Cooking Vegetables Are Associated with Decreased Home Availability of Vegetables in Low-Income Households. Nutrients. 2020;12(6):1823. Published 2020 Jun 18. doi:10.3390/nu12061823 | Study design
450 | Lane G, Nisbet C, Vatanparast H. Dietary habits of newcomer children in Canada. Public Health Nutr. 2019;22:3151-3162. doi:10.1017/s1368980019001964. | Study design
451 | Langer SL, Seburg E, JaKa MM, et al. Predicting dietary intake among children classified as overweight or at risk for overweight: Independent and interactive effects of parenting practices and styles. Appetite. 2017;110:72-79. doi:10.1016/j.appet.2016.12.011. | Study design
452 | Larsen H, Hermans RCJ, Kayabal S, et al. Associations between parental and pre-adolescents’ physical activity and diet quality: The role of parental child care involvementand child’s sex. Eat Behav. 2023;50:101775. doi:10.1016/j.eatbeh.2023.101775. | Study design
453 | Larson N, Eisenberg ME, Berge JM, et al. Ethnic/racial disparities in adolescents’ home food environments and linkages to dietary intake and weight status. Eat Behav. 2015;16:43-6. doi:10.1016/j.eatbeh.2014.10.010. | Study design
454 | Larson N, Fulkerson J, Story M, et al. Shared meals among young adults are associated with better diet quality and predicted by family meal patterns during adolescence. Public Health Nutr. 2013;16:883-93. doi:10.1017/s1368980012003539. | Intervention/exposure
455 | Larson N, Miller JM, Eisenberg ME, et al. Multicontextual correlates of energy-dense, nutrient-poor snack food consumption by adolescents. Appetite. 2017;112:23-34. doi:10.1016/j.appet.2017.01.008. | Study design
456 | Larson N, Wang Q, Berge JM, et al. Eating breakfast together as a family: mealtime experiences and associations with dietary intake among adolescents in rural Minnesota, USA. Public Health Nutr. 2016;19:1565-74. doi:10.1017/s1368980016000379. | Study design
457 | Larson NI, Nelson MC, Neumark-Sztainer D, et al. Making time for meals: meal structure and associations with dietary intake in young adults. J Am Diet Assoc. 2009;109:72-9. doi:10.1016/j.jada.2008.10.017. | Study design
458 | Larson NI, Neumark-Sztainer D, Hannan PJ, et al. Family meals during adolescence are associated with higher diet quality and healthful meal patterns during young adulthood. J Am Diet Assoc. 2007;107:1502-10. doi:10.1016/j.jada.2007.06.012. | Age of some participants at I/E
459 | Larson NI, Neumark-Sztainer DR, Harnack LJ, et al. Fruit and vegetable intake correlates during the transition to young adulthood. Am J Prev Med. 2008;35:33-37. doi:10.1016/j.amepre.2008.03.019. | Age of some participants at I/E
460 | Larson NI, Story M, Wall M, et al. Calcium and dairy intakes of adolescents are associated with their home environment, taste preferences, personal health beliefs, and meal patterns. J Am Diet Assoc. 2006;106:1816-24. doi:10.1016/j.jada.2006.08.018. | Study design
461 | Laster LER, Lovelady CA, West DG, et al. Diet quality of overweight and obese mothers and their preschool children. J Acad Nutr Diet. 2013;113:1476-1483. doi:10.1016/j.jand.2013.05.018. | Study design; Outcome
462 | Singhasai L, Phuphaibul R, Orathai P, Piaseu N, Darling-Fisher CS. Predictors of Weight Status among School-age Children. Pacific Rim International Journal of Nursing Research. 2017;21:180-194. | Study design
463 | Lazzeri G, Giallombardo D, Guidoni C, et al. Nutritional surveillance in Tuscany: eating habits at breakfast, mid-morning and afternoon snacks among 8-9 y-old children. J Prev Med Hyg. 2006;47:91-9. | Study design
464 | Le Heuzey MF, Turberg-Romain C. Nutri-bébé 2013 Study Part 3. Nutri-Bébé Survey 2013:3/Behaviour of mothers and young children during feeding. Archives de Pediatrie. 2015;22:10s20-10s29. doi:10.1016/S0929-693X(15)30742-9. | Study design
465 | Leak TM, Swenson A, Rendahl A, et al. Examining the feasibility of implementing behavioural economics strategies that encourage home dinner vegetable intake among low-income children. Public Health Nutr. 2017;20:1388-1392. doi:10.1017/s1368980017000131. | Study design
466 | LeCroy MN, Siega-Riz AM, Albrecht SS, et al. Association of food parenting practice patterns with obesogenic dietary intake in Hispanic/Latino youth: Results from the Hispanic Community Children’s Health Study/Study of Latino Youth (SOL Youth). Appetite. 2019;140:277-287. doi:10.1016/j.appet.2019.05.006. | Study design
467 | Lederer AM, King MH, Sovinski D, et al. The Impact of Family Rules on Children’s Eating Habits, Sedentary Behaviors, and Weight Status. Child Obes. 2015;11:421-9. doi:10.1089/chi.2014.0164. | Study design
468 | Lee J, Friend S, Horning ML, et al. Are patterns of family evening meal practices associated with child and parent diet quality and weight-related outcomes?. Appetite. 2022;171:105937. doi:10.1016/j.appet.2022.105937. | Study design
469 | Lee SY, Ha SA, Seo JS, et al. Eating habits and eating behaviors by family dinner frequency in the lower-grade elementary school students. Nutr Res Pract. 2014;8:679- 87. doi:10.4162/nrp.2014.8.6.679. | Study design
470 | Lee Y, Mitchell DC, Smiciklas-Wright H, Birch LL. Diet quality, nutrient intake, weight status, and feeding environments of girls meeting or exceeding recommendations for total dietary fat of the American Academy of Pediatrics. Pediatrics. 2001;107(6):E95.doi:10.1542/peds.107.6.e95 | Study design
471 | Lee Y, Mitchell DC, Smiciklas-Wright H, et al. Maternal influences on 5- to 7-year-old girls’ intake of multivitamin-mineral supplements. Pediatrics. 2002;109:E46. doi:10.1542/peds.109.3.e46. | Outcome
472 | Leech RM, McNaughton SA, Crawford DA, et al. Family food involvement and frequency of family dinner meals among Australian children aged 10-12years. Cross-sectional and longitudinal associations with dietary patterns. Appetite. 2014;75:64-70. doi:10.1016/j.appet.2013.12.021. | Intervention/exposure; Outcome
473 | Lehto E, Ray C, Haukkala A, et al. Predicting gender differences in liking for vegetables and preference for a variety of vegetables among 11-year-old children. Appetite. 2015;95:285-92. doi:10.1016/j.appet.2015.07.020. | Study design; Intervention/exposure; Outcome
474 | Lewis KH, Hsu FC, Block JP, et al. A Technology-Driven, Healthcare-Based Intervention to Improve Family Beverage Choices: Results from a Pilot Randomized Trial in the United States. Nutrients. 2023;15(9):2141. Published 2023 Apr 29. doi:10.3390/nu15092141 | Intervention/exposure; Outcome
475 | Lewis RK, Lee FA, Brown KK, et al. Youth empowerment implementation project evaluation results: A program designed to improve the health and well-being of low-income African-American adolescents. J Prev Interv Community. 2018;46:28-42. doi:10.1080/10852352.2018.1385954. | Study design; Intervention/exposure
476 | Li M, Xue H, Jia P, et al. Pocket money, eating behaviors, and weight status among Chinese children: The Childhood Obesity Study in China mega-cities. Prev Med. 2017;100:208-215. doi:10.1016/j.ypmed.2017.04.031. | Study design
477 | Liang T, Kuhle S, Veugelers PJ. Nutrition and body weights of Canadian children watching television and eating while watching television. Public Health Nutr. 2009;12:2457-63. doi:10.1017/s1368980009005564. | Study design
478 | Liem DG, Mars M, De Graaf C. Sweet preferences and sugar consumption of 4- and 5- year-old children: role of parents. Appetite. 2004;43:235-45. doi:10.1016/j.appet.2004.05.005. | Study design; Intervention/exposure
479 | Lin SF, Zive MM, Schmied E, Helm J, Ayala GX. The Effects of a Multisector, Multilevel Intervention on Child Dietary Intake: California Childhood Obesity Research Demonstration Study. Nutrients. 2023;15(20):4449. Published 2023 Oct 20. doi:10.3390/nu15204449 | Intervention/exposure; Mediating role of caergiver parenting strategies
480 | Linde JA, Horning Dehmer ML, Lee J, et al. Associations of parent dietary role modeling with children’s diet quality in a rural setting: Baseline data from the NU-HOME study. Appetite. 2022;174:106007. doi:10.1016/j.appet.2022.106007. | Study design
481 | Ling J, Chen S, Zhang N, Robbins LB, Kerver JM. Happy Family, Healthy Kids: A Healthy Eating and Stress Management Program in Low-Income Parent-Preschooler Dyads. Nurs Res. 2024;73(1):3-15. doi:10.1097/NNR.0000000000000697 | Intervention/exposure
482 | Lipsky LM, Burger K, Cummings JR, et al. Associations of parent feeding behaviors and early life food exposures with early childhood appetitive traits in an observational cohort study. Physiol Behav. 2023;265:114175. doi:10.1016/j.physbeh.2023.114175. | Outcome
483 | Lipsky LM, Haynie DL, Liu D, et al. Trajectories of eating behaviors in a nationally representative cohort of U.S. adolescents during the transition to young adulthood. Int J Behav Nutr Phys Act. 2015;12:138. doi:10.1186/s12966-015-0298-x. | Age of some participants at I/E
484 | Lipsky LM, Nansel TR, Haynie DL, et al. Diet quality of US adolescents during the transition to adulthood: changes and predictors. Am J Clin Nutr. 2017;105:1424-1432. doi:10.3945/ajcn.116.150029. | Age of some participants at I/E
485 | Liu X, Zhou Q, Clarke K, et al. Maternal feeding practices and toddlers’ fruit and vegetable consumption: results from the DIT-Coombe Hospital birth cohort in Ireland. Nutr J. 2021;20:84. doi:10.1186/s12937-021-00743-z. | Study design
486 | Lo K, Cheung C, Lee A, et al. Associations between Parental Feeding Styles and Childhood Eating Habits: A Survey of Hong Kong Pre-School Children. PLoS One. 2015;10:e0124753. doi:10.1371/journal.pone.0124753. | Study design
487 | Lohse B, Cunningham-Sabo L. Eating competence of Hispanic parents is associated with attitudes and behaviors that may mediate fruit and vegetable-related behaviors of4th grade youth. J Nutr. 2012;142:1903-9. doi:10.3945/jn.112.164269. | Study design
488 | Lohse B, Pflugh Prescott M, Cunningham-Sabo L. Eating Competent Parents of 4th Grade Youth from a Predominantly Non-Hispanic White Sample Demonstrate More Healthful Eating Behaviors than Non-Eating Competent Parents. Nutrients. 2019;11(7):1501. Published 2019 Jun 30. doi:10.3390/nu11071501 | Study design
489 | Longbottom PJ, Wrieden WL, Pine CM. Is there a relationship between the food intakes of Scottish 5 1/2 - 8 1/2-year-olds and those of their mothers?. Journal of Human Nutrition & Dietetics. 2002;15:271-279. doi:10.1046/j.1365-277x.2002.00374.x. | Intervention/exposure
490 | Looney ShannonM, Raynor HollieA. Impact of Portion Size and Energy Density on Snack Intake in Preschool-Aged Children. J Am Diet Assoc. 2011;111:414-418. doi:10.1016/j.jada.2010.11.016. | Intervention/exposure
491 | Looney SM, Raynor HA. Examining the effect of three low-intensity pediatric obesity interventions: a pilot randomized controlled trial. Clin Pediatr (Phila). 2014;53:1367-74. doi:10.1177/0009922814541803. | Intervention/exposure
492 | Lopez NV, Ayala GX, Corder K, et al. Parent support and parent-mediated behaviors are associated with children’s sugary beverage consumption. J Acad Nutr Diet. 2012;112:541-7. doi:10.1016/j.jand.2011.11.013. | Study design
493 | Lopez NV, Lai MH, Yang CH, et al. Associations of Maternal and Paternal Parenting Practices With Children’s Fruit and Vegetable Intake and Physical Activity: Preliminary Findings From an Ecological Momentary Study. JMIR Form Res. 2022;6:e38326. doi:10.2196/38326. | Age of some participants at I/E
494 | Lopez NV, Schembre S, Belcher BR, et al. Parenting styles, food-related parenting practices, and children’s healthy eating: A mediation analysis to examine relationships between parenting and child diet. Appetite. 2018;128:205-213. doi:10.1016/j.appet.2018.06.021. | Study design
495 | López-Contreras IN, Vilchis-Gil J, Klünder-Klünder M, et al. Dietary habits and metabolic response improve in obese children whose mothers received an intervention to promote healthy eating: randomized clinical trial. BMC Public Health. 2020;20:1240. doi:10.1186/s12889-020-09339-4. | Intervention/exposure
496 | Lora KR, Branscum PW, Chen S, et al. Home Food Environment Factors Associated With Hispanic Preschoolers’ Intake of Fruits and Vegetables. Fam Community Health. 2019;42:261-270. doi:10.1097/fch.0000000000000235. | Study design
497 | Lora KR, Hubbs-Tait L, Ferris AM, et al. African-American and Hispanic children’s beverage intake: Differences in associations with desire to drink, fathers’ feeding practices, and weight concerns. Appetite. 2016;107:558-567. doi:10.1016/j.appet.2016.09.012. | Study design
498 | Lora KR, Hubbs-Tait L, Guzman M, et al. Preschoolers’ influence on and help with beverage selection at the grocery store is linked to maternal responsiveness and child beverage intake: An exploratory study. Eat Behav. 2016;23:19-23. doi:10.1016/j.eatbeh.2016.07.008. | Study design
499 | Loth KA, Fertig A, Trofholz A, et al. Concordance of children’s intake of selected food groups as reported by parents via 24-h dietary recall and ecological momentary assessment. Public Health Nutr. 2021;24:22-33. doi:10.1017/s1368980020001111. | Study design
500 | Loth KA, Friend S, Horning ML, et al. Directive and non-directive food-related parenting practices: Associations between an expanded conceptualization of food-related parenting practices and child dietary intake and weight outcomes. Appetite. 2016;107:188-195. doi:10.1016/j.appet.2016.07.036. | Study design
501 | Loth KA, MacLehose RF, Larson N, et al. Food availability, modeling and restriction: How are these different aspects of the family eating environment related to adolescent dietary intake?. Appetite. 2016;96:80-86. doi:10.1016/j.appet.2015.08.026. | Study design
502 | Lotrean LM, Tutui I. Individual and familial factors associated with fruit and vegetable intake among 11- to 14-year-old Romanian school children. Health Soc Care Community. 2015;23:541-9. doi:10.1111/hsc.12166. | Study design
503 | Loucaides CA, Jago R, Theophanous M. Social, attitudinal and behavioural correlates of fruit and vegetable consumption among Cypriot adolescents. Public Health Nutr.2011;14:2139-47. doi:10.1017/s1368980011000784. | Study design
504 | Lu J, Xiong S, Arora N, et al. Using food as reinforcer to shape children’s non-food behavior: The adverse nutritional effect doubly moderated by reward sensitivity and gender. Eat Behav. 2015;19:94-7. doi:10.1016/j.eatbeh.2015.07.003. | Study design
505 | Lumeng JC, Kaciroti N, Retzloff L, et al. Longitudinal associations between maternal feeding and overweight in low-income toddlers. Appetite. 2017;113:23-29. doi:10.1016/j.appet.2017.02.016. | Outcome
506 | Luszczynska A, de Wit JB, de Vet E, et al. At-home environment, out-of-home environment, snacks and sweetened beverages intake in preadolescence, early and mid-adolescence: the interplay between environment and self-regulation. J Youth Adolesc. 2013;42:1873-83. doi:10.1007/s10964-013-9908-6. | Study design
507 | Lytle LA, Kubik MY, Perry C, et al. Influencing healthful food choices in school and home environments: results from the TEENS study. Prev Med. 2006;43:8-13. doi:10.1016/j.ypmed.2006.03.020. | Intervention/exposure; Outcome
508 | Lytle LA, Varnell S, Murray DM, et al. Predicting adolescents’ intake of fruits and vegetables. J Nutr Educ Behav. 2003;35:170-5. doi:10.1016/s1499-4046(06)60331-x. | Intervention/exposure
509 | Ma Z, Hample D. Modeling Parental Influence on Teenagers’ Food Consumption: An Analysis Using the Family Life, Activity, Sun, Health, and Eating (FLASHE) Survey. J Nutr Educ Behav. 2018;50:1005-1014. doi:10.1016/j.jneb.2018.07.005. | Study design
510 | MacFarlane A, Cleland V, Crawford D, et al. Longitudinal examination of the family food environment and weight status among children. Int J Pediatr Obes. 2009;4:343-52. doi:10.3109/17477160902846211. | Outcome
511 | MacFarlane A, Crawford D, Worsley A. Associations between parental concern for adolescent weight and the home food environment and dietary intake. J Nutr Educ Behav. 2010;42:152-60. doi:10.1016/j.jneb.2008.11.004. | Study design
512 | Machado BC, Dias P, Lima VS, et al. Prevalence and correlates of picky eating in preschool-aged children: A population-based study. Eat Behav. 2016;22:16-21. doi:10.1016/j.eatbeh.2016.03.035. | Study design
513 | Magarey A, Mauch C, Mallan K, et al. Child dietary and eating behavior outcomes up to 3.5 years after an early feeding intervention: The NOURISH RCT. Obesity (Silver Spring). 2016;24:1537-45. doi:10.1002/oby.21498. | Age of some participants at I/E
514 | Mahmood L, González-Gil EM, Schwarz P, et al. Frequency of family meals and food consumption in families at high risk of type 2 diabetes: the Feel4Diabetes-study. Eur J Pediatr. 2022;181:2523-2534. doi:10.1007/s00431-022-04445-4. | Study design
515 | Mak TN, Prynne CJ, Cole D, et al. Assessing eating context and fruit and vegetable consumption in children: new methods using food diaries in the UK National Diet and Nutrition Survey Rolling Programme. Int J Behav Nutr Phys Act. 2012;9:126. doi:10.1186/1479-5868-9-126. | Study design
516 | Makansi N, Allison P, Awad M, et al. Fruit and vegetable intake among Emirati adolescents: a mixed methods study. East Mediterr Health J. 2018;24:653-663. doi:10.26719/2018.24.7.653. | Study design
517 | Makri R, Katsoulis M, Fotiou A, et al. Prevalence of Overweight and Obesity and Associated Diet-Related Behaviours and Habits in a Representative Sample of Adolescents in Greece. Children (Basel). 2022;9(1):119. Published 2022 Jan 17. doi:10.3390/children9010119 | Study design; Outcome
518 | Małachowska A, Jeżewska-Zychowicz M. Does Examining the Childhood Food Experiences Help to Better Understand Food Choices in Adulthood?. Nutrients. 2021;13(3):983. Published 2021 Mar 18. doi:10.3390/nu13030983 | Study design
519 | Mallan KM, Fildes A, Magarey AM, et al. The Relationship between Number of Fruits, Vegetables, and Noncore Foods Tried at Age 14 Months and Food Preferences, Dietary Intake Patterns, Fussy Eating Behavior, and Weight Status at Age 3.7 Years. J Acad Nutr Diet. 2016;116:630-7. doi:10.1016/j.jand.2015.06.006. | Intervention/exposure
520 | Mantziki K, Renders CM, Vassilopoulos A, et al. Inequalities in energy-balance related behaviours and family environmental determinants in European children: changes and sustainability within the EPHE evaluation study. Int J Equity Health. 2016;15:160.doi:10.1186/s12939-016-0438-1. | Intervention/exposure
521 | Mantziki K, Vassilopoulos A, Radulian G, et al. Inequities in energy-balance related behaviours and family environmental determinants in European children: baseline results of the prospective EPHE evaluation study. BMC Public Health. 2015;15:1203. doi:10.1186/s12889-015-2540-5. | Study design
522 | Markert J, Herget S, Petroff D, et al. Telephone-based adiposity prevention for families with overweight children (T.A.F.F.-Study): one year outcome of a randomized, controlled trial. Int J Environ Res Public Health. 2014;11:10327-44. doi:10.3390/ijerph111010327. | Intervention/exposure
523 | Marlow CS, Forestell CA. The effect of parental food neophobia on children’s fruit and vegetable consumption: A serial mediation model. Appetite. 2022;172:105942. doi:10.1016/j.appet.2022.105942. | Study design
524 | Marquis M, Filion YP, Dagenais F. Does eating while watching television influence children’s food-related behaviours?. Can J Diet Pract Res. 2005;66:12-8. doi:10.3148/66.1.2005.12. | Study design; Publication language
525 | Marr C, Breeze P, Caton SJ. Examination of dietary intake of UK preschool children by varying carers: evidence from the 2008-2016 UK National Diet and Nutrition Survey. Br J Nutr. 2022;128:2063-2074. doi:10.1017/s0007114521004712. | Study design; Intervention/exposure
526 | Martens M, van Assema P, Knibbe R, et al. Family environmental factors do not explain differences in the behavioral effect of a healthy diet promotion program in lower vocational schools among 12- to 14-year-old adolescents. Am J Health Promot. 2010;24:182-5. doi:10.4278/ajhp.08041435. | Study design
527 | Martin-Biggers J, Spaccarotella K, Hongu N, et al. Translating it into real life: a qualitative study of the cognitions, barriers and supports for key obesogenic behaviors of parents of preschoolers. BMC Public Health. 2015;15:189. doi:10.1186/s12889-015- 1554-3. | Study design
528 | Martins BG, Ricardo CZ, Machado PP, et al. Eating meals with parents is associated with better quality of diet for Brazilian adolescents. Cad Saude Publica. 2019;35:e00153918. doi:10.1590/0102-311x00153918. | Study design
529 | Masento NA, Dulay KM, Harvey K, et al. Parent, child, and environmental predictors of vegetable consumption in Italian, Polish, and British preschoolers. Front Nutr. 2022;9:958245. doi:10.3389/fnut.2022.958245. | Study design
530 | Masento NA, Dulay KM, Roberts AP, et al. See and Eat! The impact of repeated exposure to vegetable ebooks on young children’s vegetable acceptance. Appetite. 2023;182:106447. doi:10.1016/j.appet.2022.106447. | Intervention/exposure
531 | Mason TB, O’Connor SG, Schembre SM, et al. Momentary affect, stress coping, and food intake in mother-child dyads. Health Psychol. 2019;38:238-247. doi:10.1037/hea0000714. | Intervention/exposure
532 | Mason TB, Smith KE, Dunton GF. Maternal parenting styles and ecological momentary assessment of maternal feeding practices and child food intake across middle childhood to early adolescence. Pediatr Obes. 2020;15:e12683. doi:10.1111/ijpo.12683. | Intervention/exposure
533 | Mason TB. Interactions of parental feeding characteristics and adolescent emotional eating in relation to unhealthful food and sugar-sweetened beverage intake among adolescents. Appetite. 2024;193:107125. doi:10.1016/j.appet.2023.107125 | Study design
534 | Mâsse LC, Blanck HM, Valente M, et al. Association between self-reported household practices and body mass index of US children and adolescents, 2005. Prev Chronic Dis. 2012;9:E174. doi:10.5888/pcd9.110149. | Study design
535 | Mâsse LC, Watts AW, Barr SI, et al. Individual and household predictors of adolescents’ adherence to a web-based intervention. Ann Behav Med. 2015;49:371-83. doi:10.1007/s12160-014-9658-z. | Outcome
536 | Matheson DM, Robinson TN, Varady A, et al. Do Mexican-American mothers’ food-related parenting practices influence their children’s weight and dietary intake?. J Am Diet Assoc. 2006;106:1861-5. doi:10.1016/j.jada.2006.08.004. | Study design
537 | Mathieu NP, Sommer EC, Mitchell SJ, et al. Urban Latino Families’ Food Built Environment and Young Children’s Produce Consumption. J Health Care Poor Underserved. 2016;27:1899-1908. doi:10.1353/hpu.2016.0170. | Study design; Intervention/exposure
538 | Matthan NR, Wylie-Rosett J, Xue X, et al. Effect of a Family-Based Intervention on Nutrient Biomarkers, Desaturase Enzyme Activities, and Cardiometabolic Risk Factors in Children with Overweight and Obesity. Curr Dev Nutr. 2020;4:nzz138. doi:10.1093/cdn/nzz138. | Intervention/exposure; Outcome
539 | McDonald JA, Sroka CJ, Olivares E, et al. Intrafamilial Characteristics Are Important Predictors of Children’s Diets in New Mexico’s Border Colonias. Health Promot Pract. 2022;23:1050-1062. doi:10.1177/15248399211045680. | Study design
540 | McGowan L, Croker H, Wardle J, et al. Environmental and individual determinants of core and non-core food and drink intake in preschool-aged children in the United Kingdom. Eur J Clin Nutr. 2012;66:322-8. doi:10.1038/ejcn.2011.224. | Study design
541 | McIver MB, Colby S, Hansen-Petrik M, Anderson Steeves ET. Caregiver Feeding Practices as Predictors for Child Dietary Intake in Low-Income, Appalachian Communities. Nutrients. 2021;13(8):2773. Published 2021 Aug 13. doi:10.3390/nu13082773 | Study design
542 | McLeod CJ, Haycraft E, Daley AJ. Offering vegetables to children at breakfast time in nursery and kindergarten settings: the Veggie Brek feasibility and acceptability cluster randomised controlled trial. Int J Behav Nutr Phys Act. 2023;20:38. doi:10.1186/s12966- 023-01443-z. | Intervention/exposure
543 | McManus MA, Khalessi AA, Lin J, et al. Positive feelings during pregnancy, early feeding practices, and infant health. Pediatr Int. 2017;59:593-599. doi:10.1111/ped.13209. | Intervention/exposure; Outcome
544 | Mekonnen T, Papadopoulou E, Lien N, et al. Mediators of parental educational differences in the intake of carbonated sugar-sweetened soft drinks among adolescents, and the moderating role of neighbourhood income. Nutr J. 2023;22:43. doi:10.1186/s12937-023-00872-7. | Study design
545 | Melbye EL, Øverby NC, Øgaard T. Child consumption of fruit and vegetables: the roles of child cognitions and parental feeding practices. Public Health Nutr. 2012;15:1047-55. doi:10.1017/s1368980011002679. | Study design
546 | Mendoza-Herrera K, Monge-Rojas R, O’Neill J, Smith-Castro V, Mattei J. Association between Parental Feeding Styles and Excess Weight, and Its Mediation by Diet, in Costa Rican Adolescents. Nutrients. 2022;14(11):2314. Published 2022 May 31. doi:10.3390/nu14112314 | Study design
547 | Mennella JA, Smethers AD, Decker JE, Delahanty MT, Stallings VA, Trabulsi JC. Effects of Early Weight Gain Velocity, Diet Quality, and Snack Food Access on Toddler Weight Status at 1.5 Years: Follow-Up of a Randomized Controlled Infant Formula Trial. Nutrients. 2021;13(11):3946. Published 2021 Nov 4. doi:10.3390/nu13113946 | Intervention/exposure; Outcome
548 | Mérida Rios L, Márquez Serrano M, Jiménez Aguilar A, et al. Promoting fruit, vegetable and simple water consumption among mothers and teachers of preschool children: An Intervention Mapping initiative. Eval Program Plann. 2019;76:101675. doi:10.1016/j.evalprogplan.2019.101675. | Intervention/exposure; Age of some participants at I/E
549 | Michels N, Vynckier L, Moreno LA, et al. Mediation of psychosocial determinants in the relation between socio-economic status and adolescents’ diet quality. Eur J Nutr. 2018;57:951-963. doi:10.1007/s00394-017-1380-8. | Study design
550 | Michou M, Panagiotakos DB, Mamalaki E, et al. Development and validation of the Greek version of the comprehensive parental feeding questionnaire. Mediterranean Journal of Nutrition and Metabolism. 2019;12:211-221. doi:10.3233/MNM-180275. | Study design; Outcome
551 | Mihrshahi S, Foley B, Nguyen B, et al. Evaluation of the Cancer Council NSW Eat It To Beat It Healthy Lunch Box Sessions: A short intervention to promote the intake of fruit and vegetables among families of primary school children in NSW Australia. Health Promot J Austr. 2019;30:102-107. doi:10.1002/hpja.23. | Intervention/exposure; Outcome
552 | Miller A, Franzen-Castle L, Aguirre T, et al. Food-related behavior and intake of adult main meal preparers of 9-10 year-old children participating in iCook 4-H: A five-state childhood obesity prevention pilot study. Appetite. 2016;101:163-70. doi:10.1016/j.appet.2016.03.006. | Intervention/exposure; Outcome
553 | Mirotta JA, Darlington GA, Buchholz AC, et al. Guelph Family Health Study’s Home-Based Obesity Prevention Intervention Increases Fibre and Fruit Intake in Preschool-Aged Children. Can J Diet Pract Res. 2018;79:86-90. doi:10.3148/cjdpr-2017-036. | Intervention/exposure
554 | Mittmann Silke, Austel Anja, Ellrott Thomas. Behavioural effects of a short school-based fruit and vegetable promotion programme. Health Education. 2016;116:222-237. doi:10.1108/HE-04-2014-0062. | Study design; Intervention/exposure
555 | Mokhtari F, Kazemi A, Ehsanpour S. Effect of educational intervention program for parents on adolescents’nutritional behaviors in Isfahan in 2016. J Educ Health Promot. 2017;6:103. doi:10.4103/jehp.jehp_155_16. | Intervention/exposure
556 | Möller LM, de Hoog ML, van Eijsden M, et al. Infant nutrition in relation to eating behaviour and fruit and vegetable intake at age 5 years. Br J Nutr. 2013;109:564-71. doi:10.1017/s0007114512001237. | Intervention/exposure
557 | Monastra MA, Bordin J, Wolff CB. LEAP works! Outcomes of a family-based nutrition education and physical activity promotion program. Californian Journal of Health Promotion. 2005;3:43-60. | Intervention/exposure
558 | Monge-Rojas R, Nuñez HP, Garita C, et al. Psychosocial aspects of Costa Rican adolescents’ eating and physical activity patterns. J Adolesc Health. 2002;31:212-9. doi:10.1016/s1054-139x(02)00376-2. | Study design
559 | Monge-Rojas R, Smith-Castro V, Colon-Ramos U, et al. Parental feeding styles and adolescents’ healthy eating habits. Structure and correlates of a Costa Rican questionnaire. Appetite. 2010;55:253-62. doi:10.1016/j.appet.2010.06.010. | Study design
560 | Monge-Rojas R, Smith-Castro V, O’Connor T, et al. Intersectionality between parenting styles, area of residence and gender on food group consumption among Costa Rican adolescents. Appetite. 2021;166:105443. doi:10.1016/j.appet.2021.105443. | Study design
561 | Monroe-Lord L, Anderson A, Jones BL, et al. Relationship between Family Racial/Ethnic Backgrounds, Parenting Practices and Styles, and Adolescent Eating Behaviors. Int J Environ Res Public Health. 2022;19(12):7388. Published 2022 Jun 16. doi:10.3390/ijerph19127388 | Study design
562 | Monroe-Lord L, Jones BL, Richards R, et al. Parenting Practices and Adolescents’ Eating Behaviors in African American Families. Int J Environ Res Public Health. 2021;19(1):110. Published 2021 Dec 23. doi:10.3390/ijerph19010110 | Study design
563 | Montaño Z, Smith JD, Dishion TJ, Shaw DS, Wilson MN. Longitudinal relations between observed parenting behaviors and dietary quality of meals from ages 2 to 5. Appetite. 2015;87:324-329. doi:10.1016/j.appet.2014.12.219 | Outcome
564 | Moores CJ, Miller J, Daniels LA, et al. Pre-post evaluation of a weight management service for families with overweight and obese children, translated from the efficacious lifestyle intervention Parenting, Eating and Activity for Child Health (PEACH). Br J Nutr. 2018;119:1434-1445. doi:10.1017/s0007114518001083. | Study design
565 | Moreira CC, Moreira EA, Fiates GM. Perceived purchase of healthy foods is associated with regular consumption of fruits and vegetables. J Nutr Educ Behav. 2015;47:248-52. doi:10.1016/j.jneb.2014.12.003. | Study design
566 | Moreira I, Severo M, Oliveira A, et al. Social and health behavioural determinants of maternal child-feeding patterns in preschool-aged children. Matern Child Nutr. 2016;12:314-25. doi:10.1111/mcn.12132. | Study design
567 | Morrison H, Power TG, Nicklas T, et al. Exploring the effects of maternal eating patterns on maternal feeding and child eating. Appetite. 2013;63:77-83. doi:10.1016/j.appet.2012.12.017. | Study design
568 | Mosli RH, Kutbi HA. The association of early feeding practices with eating behaviors and maternal indulgent feeding behaviors among Saudi preschoolers. Front Psychol. 2023;14:1126687. doi:10.3389/fpsyg.2023.1126687. | Study design; Outcome
569 | Mosli RH. The association between sibship composition and maternal feeding behaviors. Progress in Nutrition. 2021;23 doi:10.23751/pn.v23i3.11834. | Study design
570 | Moura AF, Grønhøj A, Aschemann-Witzel J. Spicing up food interactions: Development of a healthy food education activity targeting fathers and their young children. J Hum Nutr Diet. 2023;36:1795-1810. doi:10.1111/jhn.13179. | Study design
571 | Munday K, Wilson M. Implementing a Health and Wellbeing Programme for Children in Early Childhood: A Preliminary Study. Nutrients. 2017;9(9):1031. Published 2017 Sep18. doi:10.3390/nu9091031 | Intervention/exposure
572 | Murashima M, Hoerr SL, Hughes SO, et al. Maternal parenting behaviors during childhood relate to weight status and fruit and vegetable intake of college students. J Nutr Educ Behav. 2012;44:556-63. doi:10.1016/j.jneb.2011.05.008. | Study design
573 | Musaad SM, Donovan SM, Fiese BH. Parental perception of child weight in the first two years-of-life: a potential link between infant feeding and preschoolers’ diet. Appetite. 2015;91:90-100. doi:10.1016/j.appet.2015.03.029. | Study design; Intervention/exposure
574 | Mushaphi LF, Dannhauser A, Walsh CM, et al. The impact of a nutrition education programme on feeding practices of caregivers with children aged 3 to 5 years in rural Limpopo province, South Africa. South African Journal of Clinical Nutrition. 2017;30:101- 108. doi:10.1080/16070658.2017.1322823. | Intervention/exposure
575 | Nabors L, Murphy MJ, Lusky C, et al. Using Photovoice to Improve Healthy Eating for Children Participating in an Obesity Prevention Program. Glob Pediatr Health. 2020;7:2333794x20954673. doi:10.1177/2333794x20954673. | Intervention/exposure
576 | Nakamura MS, Huelsnitz CO, Rothman AJ, et al. Associations Between Parents’ Health and Social Control Behaviors and Their Adolescent’s Self-Efficacy and Health Behaviors: Insights From the Family Life, Activity, Sun, Health, and Eating (FLASHE) survey. Ann Behav Med. 2022;56:920-932. doi:10.1093/abm/kaab113. | Study design
577 | Nanjappa S, Hector M, Marcenes W. Mother’s Perception of General Family Functioning and Sugar Consumption of 3- and 4-Year-Old Children: The East London Family Study. Caries Res. 2015;49:515-22. doi:10.1159/000431234. | Study design
578 | Natale RA, Atem F, Weerakoon S, et al. An Implementation Approach Comparison of a Child Care Center-Based Obesity Prevention Program. J Dev Behav Pediatr. 2021;42:135-145. doi:10.1097/dbp.0000000000000861. | Intervention/exposure
579 | Natale RA, Lopez-Mitnik G, Uhlhorn SB, et al. Effect of a child care center-based obesity prevention program on body mass index and nutrition practices among preschool-aged children. Health Promot Pract. 2014;15:695-705. doi:10.1177/1524839914523429. | Intervention/exposure
580 | Natale RubyR, Camejo StephanieT, Asfour Lila, et al. Promoting Healthy Weight Among Children With Developmental Delays. Journal of Early Intervention. 2017;39:51-65. doi:10.1177/1053815116689060. | Intervention/exposure; Health status
581 | Neumark-Sztainer D, Hannan PJ, Story M, et al. Family meal patterns: associations with sociodemographic characteristics and improved dietary intake among adolescents. J Am Diet Assoc. 2003;103:317-22. doi:10.1053/jada.2003.50048. | Study design
582 | Neumark-Sztainer D, MacLehose R, Loth K, et al. What’s for dinner? Types of food served at family dinner differ across parent and family characteristics. Public Health Nutr. 2014;17:145-55. doi:10.1017/s1368980012004594. | Study design
583 | Neumark-Sztainer D, Wall M, Perry C, et al. Correlates of fruit and vegetable intake among adolescents: Findings from Project EAT. Preventive Medicine. 2003;37:198-208. doi:10.1016/S0091-7435(03)00114-2. | Study design
584 | Nezami BT, Ward DS, Lytle LA, et al. A mHealth randomized controlled trial to reduce sugar-sweetened beverage intake in preschool-aged children. Pediatr Obes. 2018;13:668-676. doi:10.1111/ijpo.12258. | Intervention/exposure
585 | Nezami BT, Wasser HM, Tate DF. Parent and child dietary changes in a 6-month mobile-delivered weight loss intervention with tailored messaging for parents. Front Public Health. 2022;10:972109. doi:10.3389/fpubh.2022.972109. | Intervention/exposure
586 | Ng CM, Kaur S, Koo HC, et al. Culinary Nutrition Education Improves Home Food Availability and Psychosocial Factors Related to Healthy Meal Preparation Among Children. J Nutr Educ Behav. 2022;54:100-108. doi:10.1016/j.jneb.2021.04.006. | Outcome
587 | Niemeier BS, Duan YP, Shang BR, et al. Parental influences on weight-related health behaviors in western and eastern cultures. Child Care Health Dev. 2017;43:259-266. doi:10.1111/cch.12438. | Study design; Intervention/exposure; Outcome
588 | Niermann C, Krapf F, Renner B, et al. Family health climate scale (FHC-scale): development and validation. Int J Behav Nutr Phys Act. 2014;11:30. doi:10.1186/1479- 5868-11-30. | Intervention/exposure; Outcome
589 | Norton L, Parkinson J, Harris N, Hart LM. What Factors Predict the Use of Coercive Food Parenting Practices among Mothers of Young Children? An Examination of Food Literacy, Disordered Eating and Parent Demographics. Int J Environ Res Public Health.2021;18(19):10538. Published 2021 Oct 8. doi:10.3390/ijerph181910538 | Study design
590 | Nyberg G, Sundblom E, Norman. Effectiveness of a universal parental support programme to promote healthy dietary habits and physical activity and to prevent overweight and obesity in 6-year-old children: the Healthy School Start Study, a cluster-randomised controlled trial. PLoS One. 2015;10:e0116876. doi:10.1371/journal.pone.0116876. | Intervention/exposure
591 | Nyström CD, Sandin S, Henriksson P, et al. Mobile-based intervention intended to stop obesity in preschool-aged children: the MINISTOP randomized controlled trial. Am J Clin Nutr. 2017;105:1327-1335. doi:10.3945/ajcn.116.150995. | Intervention/exposure
592 | Ochoa-Avilés A, Verstraeten R, Huybregts L, et al. A school-based intervention improved dietary intake outcomes and reduced waist circumference in adolescents: a cluster randomized controlled trial. Nutr J. 2017;16:79. doi:10.1186/s12937-017-0299-5. | Intervention/exposure
593 | O’Connell ML, Henderson KE, Luedicke J, et al. Repeated exposure in a natural setting: a preschool intervention to increase vegetable consumption. J Acad Nutr Diet. 2012;112:230-4. doi:10.1016/j.jada.2011.10.003. | Intervention/exposure; Outcome
594 | O’Connor SG, Huh J, Schembre SM, et al. The Association of Maternal Perceived Stress With Changes in Their Children’s Healthy Eating Index (HEI-2010) Scores Over Time. Ann Behav Med. 2019;53:877-885. doi:10.1093/abm/kay095. | Intervention/exposure
595 | O’Connor TM, Elias C, Thompson RR, et al. The association of TV viewing during dinner meals with quality of dietary intake and BMI z-scores among low income, ethnic minority preschool children. Appetite. 2019;140:231-238. doi:10.1016/j.appet.2019.05.023. | Study design
596 | Odoms-Young AM, Kong A, Schiffer LA, et al. Evaluating the initial impact of the revised Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) food packages on dietary intake and home food availability in African-American and Hispanic families. Public Health Nutr. 2014;17:83-93. doi:10.1017/s1368980013000761. | Intervention/exposure
597 | O’Donovan SM, Murray DM, Hourihane JO, et al. Adherence with early infant feeding and complementary feeding guidelines in the Cork BASELINE Birth Cohort Study. Public Health Nutr. 2015;18:2864-73. doi:10.1017/s136898001500018x. | Intervention/exposure; Outcome
598 | O’Halloran SA, Eksteen G, Polayya N, Ropertz M, Senekal M. The Food Environment of Primary School Learners in a Low-to-Middle-Income Area in Cape Town, South Africa. Nutrients. 2021;13(6):2043. Published 2021 Jun 15. doi:10.3390/nu13062043 | Study design; Outcome
599 | Ohly H, Pealing J, Hayter AK, et al. Parental food involvement predicts parent and child intakes of fruits and vegetables. Appetite. 2013;69:8-14. doi:10.1016/j.appet.2013.05.003. | Study design; Intervention/exposure
600 | Olvera Norma. Commentary on ‘Exploring the Association Between Household Food Insecurity, Parental Self-Efficacy and Fruit and Vegetable Parenting Practices Among Parents of 5- to 8-Year-Old Overweight Children’. Journal of Applied Research on Children. 2012;3:1-2. doi:10.58464/2155-5834.1081. | Study design; Publication status
601 | Orehek E, Ferrer R. Parent Instrumentality for Adolescent Eating and Activity. Ann Behav Med. 2019;53:652-664. doi:10.1093/abm/kay074. | Study design
602 | Orrell-Valente JK, Hill LG, Brechwald WA, et al. “Just three more bites”: an observational analysis of parents’ socialization of children’s eating at mealtime. Appetite. 2007;48:37-45. doi:10.1016/j.appet.2006.06.006. | Study design; Outcome
603 | Orün E, Erdil Z, Cetinkaya S, et al. Problematic eating behaviour in Turkish children aged 12-72 months: characteristics of mothers and children. Cent Eur J Public Health. 2012;20:257-61. doi:10.21101/cejph.a3748. | Study design; Outcome
604 | Osborne CL, Forestell CA. Increasing children’s consumption of fruit and vegetables: does the type of exposure matter?. Physiol Behav. 2012;106:362-8. doi:10.1016/j.physbeh.2012.01.006. | Intervention/exposure
605 | O’Sullivan A, Fitzpatrick N, Doyle O. Effects of early intervention on dietary intake and its mediating role on cognitive functioning: a randomised controlled trial. Public Health Nutr. 2017;20:154-164. doi:10.1017/s1368980016001877. | Intervention/exposure
606 | Othman SI, Fertig A, Trofholz A, et al. How time in the US and race/ethnicity shape food parenting practices and child diet quality. Appetite. 2022;171:105870.doi:10.1016/j.appet.2021.105870. | Study design
607 | Overcash F, Davey C, Zhang Y, Reicks M. Evening Meal Types and Family Meal Characteristics: Associations with Demographic Characteristics and Food Intake among Adolescents. Nutrients. 2020;12(4):886. Published 2020 Mar 25. doi:10.3390/nu12040886 | Study design
608 | Overcash F, Ritter A, Mann T, et al. Impacts of a Vegetable Cooking Skills Program Among Low-Income Parents and Children. J Nutr Educ Behav. 2018;50:795-802. doi:10.1016/j.jneb.2017.10.016. | Intervention/exposure; Outcome
609 | Overcash FM, Vickers Z, Ritter AE, et al. An in-home intervention of parent-implemented strategies to increase child vegetable intake: results from a non-randomized cluster-allocated community trial. BMC Public Health. 2019;19:881. doi:10.1186/s12889-019- 7079-4. | Age of some participants at I/E
610 | Ozturk Sibel, Yildiz Esra. The Psychometric Properties of the Turkish Version of the Caregiver’s Feeding Styles Questionnaire. International Journal of Caring Sciences. 2018;11:812-818. | Study design; Outcome
611 | Molina P, Coloma MJ, Gálvez P, Stecher MJ, Vizcarra M, Schwingel A. Food Parenting Practices Promoted by Childcare and Primary Healthcare Centers in Chile: What Influences Do These Practices Have on Parents? A Qualitative Study. Children (Basel). 2023;10(12):1875. Published 2023 Nov 29. doi:10.3390/children10121875 | Study design
612 | Palfreyman Z, Haycraft E, Meyer C. Development of the Parental Modelling of Eating Behaviours Scale (PARM): links with food intake among children and their mothers. Matern Child Nutr. 2014;10:617-29. doi:10.1111/j.1740-8709.2012.00438.x. | Study design
613 | Papaioannou MA, Cross MB, Power TG, et al. Feeding style differences in food parenting practices associated with fruit and vegetable intake in children from low-income families. J Nutr Educ Behav. 2013;45:643-51. doi:10.1016/j.jneb.2013.05.007. | Study design
614 | Papas MA, Hurley KM, Quigg AM, et al. Low-income, African American adolescent mothers and their toddlers exhibit similar dietary variety patterns. J Nutr Educ Behav. 2009;41:87-94. doi:10.1016/j.jneb.2008.01.005. | Intervention/exposure
615 | Parada H, Ayala GX, Horton LA, et al. Latino fathers’ feeding-related parenting strategies on children’s eating. Ecol Food Nutr. 2016;55:292-307. doi:10.1080/03670244.2016.1161616. | Study design
616 | Park S, Li R, Birch L. Mothers’ child-feeding practices are associated with children’s sugar-sweetened beverage intake. J Nutr. 2015;145:806-12. doi:10.3945/jn.114.207233. | Study design
617 | Parks CA, Blaser C, Smith TM, et al. Correlates of fruit and vegetable intake among parents and adolescents: findings from the Family Life, Activity, Sun, Health, and Eating (FLASHE) study. Public Health Nutr. 2018;21:2079-2087. doi:10.1017/s1368980018000770. | Study design
618 | Patrick H, Nicklas TA, Hughes SO, et al. The benefits of authoritative feeding style: caregiver feeding styles and children’s food consumption patterns. Appetite. 2005;44:243-9. doi:10.1016/j.appet.2002.07.001. | Study design
619 | Pearson N, Atkin AJ, Biddle SJ, et al. A family-based intervention to increase fruit and vegetable consumption in adolescents: a pilot study. Public Health Nutr. 2010;13:876-85. doi:10.1017/s1368980010000121. | Age of some participants at I/E
620 | Pearson N, Atkin AJ, Biddle SJ, et al. Parenting styles, family structure and adolescent dietary behaviour. Public Health Nutr. 2010;13:1245-53. doi:10.1017/s1368980009992217. | Study design
621 | Pearson N, Ball K, Crawford D. Parental influences on adolescent fruit consumption: the role of adolescent self-efficacy. Health Educ Res. 2012;27:14-23. doi:10.1093/her/cyr051. | Study design
622 | Pearson N, Ball K, Crawford D. Predictors of changes in adolescents’ consumption of fruits, vegetables and energy-dense snacks. Br J Nutr. 2011;105:795-803. doi:10.1017/s0007114510004290. | Age of some participants at I/E
623 | Pearson N, Biddle SJH, Griffiths P, et al. Clustering and correlates of screen-time and eating behaviours among young children. BMC Public Health. 2018;18:753. doi:10.1186/s12889-018-5698-9. | Study design
624 | Pearson N, Biddle SJH, Griffiths P, et al. Reducing screen-time and unhealthy snacking in 9-11 year old children: the Kids FIRST pilot randomised controlled trial. BMC Public Health. 2020;20:122. doi:10.1186/s12889-020-8232-9. | Study design; Intervention/exposure
625 | Pearson N, Finch M, Sutherland R, et al. An mHealth Intervention to Reduce the Packing of Discretionary Foods in Children’s Lunch Boxes in Early Childhood Education and Care Services: Cluster Randomized Controlled Trial. J Med Internet Res. 2022;24(3):e27760. Published 2022 Mar 17. doi:10.2196/27760 | Intervention/exposure
626 | Pearson N, Griffiths P, Biddle SJ, et al. Clustering and correlates of screen-time and eating behaviours among young adolescents. BMC Public Health. 2017;17:533. doi:10.1186/s12889-017-4441-2. | Study design
627 | Pearson N, Griffiths P, Biddle SJH, et al. Individual, behavioural and home environmental factors associated with eating behaviours in young adolescents. Appetite. 2017;112:35-43. doi:10.1016/j.appet.2017.01.001. | Study design
628 | Pearson N, Timperio A, Salmon J, et al. Family influences on children’s physical activity and fruit and vegetable consumption. Int J Behav Nutr Phys Act. 2009;6:34. doi:10.1186/1479-5868-6-34. | Study design
629 | Pedersen S, Grønhøj A, Thøgersen J. Following family or friends. Social norms in adolescent healthy eating. Appetite. 2015;86:54-60. doi:10.1016/j.appet.2014.07.030. | Study design
630 | Pemjean I, Mediano F, Ferrer P, et al. Food access, domestic environments, and dietary quality of low-middle income Chilean children during the COVID-19 pandemic. Front Public Health. 2023;11:1164357. doi:10.3389/fpubh.2023.1164357. | INCLUDE; Intervention/exposure
631 | Penilla C, Tschann JM, Sanchez-Vaznaugh EV, et al. Obstacles to preventing obesity in children aged 2 to 5 years: Latino mothers’ and fathers’ experiences and perceptions of their urban environments. Int J Behav Nutr Phys Act. 2017;14:148. doi:10.1186/s12966- 017-0605-9. | Study design; Intervention/exposure
632 | Pérez-Lizaur AB, Kaufer-Horwitz M, Plazas M. Environmental and personal correlates of fruit and vegetable consumption in low income, urban Mexican children. J Hum Nutr Diet. 2008;21:63-71. doi:10.1111/j.1365-277X.2007.00839.x. | Study design
633 | Perraud E, Parker HW, Tovar A, et al. The relationship between maternal prenatal and postnatal vegetable intake and repeated measures of infant vegetable intake frequency in a national U.S. sample. Appetite. 2022;168:105781. doi:10.1016/j.appet.2021.105781. | Intervention/exposure
634 | Persky S, Ferrer RA, Klein WMP, et al. Effects of Fruit and Vegetable Feeding Messages on Mothers and Fathers: Interactions Between Emotional State and Health Message Framing. Ann Behav Med. 2019;53:789-800. doi:10.1093/abm/kay088. | Intervention/exposure; Outcome
635 | Persky S, Yaremych HE, Goldring MR, et al. Investigating the Efficacy of Genetic, Environmental, and Multifactorial Risk Information When Communicating Obesity Risk to Parents of Young Children. Ann Behav Med. 2021;55:720-733. doi:10.1093/abm/kaaa103. | Intervention/exposure; Outcome
636 | Pesch MH, Appugliese DP, Kaciroti N, et al. Maternal encouragement and discouragement: Differences by food type and child weight status. Appetite. 2016;101:15-22. doi:10.1016/j.appet.2016.02.146. | Study design
637 | Pettigrew S, Jongenelis M, Chapman K, et al. Factors influencing the frequency of children’s consumption of soft drinks. Appetite. 2015;91:393-8. doi:10.1016/j.appet.2015.04.080. | Study design
638 | Petty ML, Escrivão MA, Souza AA. Preliminary validation of the Parent Mealtime Action Scale and its association with food intake in children from São Paulo, Brazil. Appetite. 2013;62:166-72. doi:10.1016/j.appet.2012.11.024. | Study design
639 | Philips N, Sioen I, Michels N, et al. The influence of parenting style on health related behavior of children: findings from the ChiBS study. Int J Behav Nutr Phys Act. 2014;11:95. doi:10.1186/s12966-014-0095-y. | Study design
640 | Pinket AS, De Craemer M, De Bourdeaudhuij I, et al. Can Parenting Practices Explain the Differences in Beverage Intake According to Socio-Economic Status: The Toybox-Study. Nutrients. 2016;8(10):591. Published 2016 Sep 23. doi:10.3390/nu8100591 | Study design
641 | Pinket AS, De Craemer M, Huybrechts I, et al. Multibehavioural Interventions with a Focus on Specific Energy Balance-Related Behaviours Can Affect Diet Quality in Preschoolers from Six European Countries: The ToyBox-Study. Nutrients. 2017;9(5):479.Published 2017 May 10. doi:10.3390/nu9050479 | Intervention/exposure
642 | Pinket AS, Van Lippevelde W, De Bourdeaudhuij I, et al. Effect and Process Evaluation of a Cluster Randomized Control Trial on Water Intake and Beverage Consumption in Preschoolers from Six European Countries: The ToyBox-Study. PLoS One. 2016;11:e0152928. doi:10.1371/journal.pone.0152928. | Intervention/exposure
643 | Poulos NS, Pasch KE, Springer AE, et al. Is frequency of family meals associated with parental encouragement of healthy eating among ethnically diverse eighth graders?. Public Health Nutr. 2014;17:998-1003. doi:10.1017/s1368980013001092. | Study design; Outcome
644 | Poulsen MN, Hosterman JF, Wood GC, et al. Family-Based Telehealth Initiative to Improve Nutrition and Physical Activity for Children With Obesity and Its Utility During COVID-19: A Mixed Methods Evaluation. Front Nutr. 2022;9:932514. doi:10.3389/fnut.2022.932514. | Intervention/exposure; Comparator
645 | Power JM, Bersamin A. A Text Messaging Intervention (Txt4HappyKids) to Promote Fruit and Vegetable Intake Among Families With Young Children: Pilot Study. JMIR Form Res. 2018;2:e13. doi:10.2196/formative.8544. | Study design; Intervention/exposure
646 | Power TG, Hughes SO, Goodell LS, et al. Feeding practices of low-income mothers: how do they compare to current recommendations?. Int J Behav Nutr Phys Act. 2015;12:34. doi:10.1186/s12966-015-0179-3. | Study design; Outcome
647 | Prado G, Fernandez A, St George SM, et al. Results of a Family-Based Intervention Promoting Healthy Weight Strategies in Overweight Hispanic Adolescents and Parents: An RCT. Am J Prev Med. 2020;59:658-668. doi:10.1016/j.amepre.2020.06.010. | Intervention/exposure
648 | Puspita E, Wulandari H, Nurhayati, et al. Hypnoparenting method to increase vegetables and fruits consumption in Kindergarten. Indian Journal of Forensic Medicine and Toxicology. 2019;13:1655-1660. doi:10.5958/0973-9130.2019.00544.9. | Intervention/exposure
649 | Quah PL, Syuhada G, Fries LR, et al. Maternal feeding practices in relation to dietary intakes and BMI in 5 year-olds in a multi-ethnic Asian population. PLoS One. 2018;13:e0203045. doi:10.1371/journal.pone.0203045. | Study design
650 | Quan T, Salomon J, Nitzke S, et al. Behaviors of low-income mothers related to fruit and vegetable consumption. J Am Diet Assoc. 2000;100:567-70. doi:10.1016/s0002- 8223(00)00173-5. | Study design; Intervention/exposure
651 | Quattlebaum M, Wilson DK, Sweeney AM, Zarrett N. Moderating Effects of Parental Feeding Practices and Emotional Eating on Dietary Intake among Overweight African American Adolescents. Nutrients. 2021;13(6):1920. Published 2021 Jun 3. doi:10.3390/nu13061920 | Study design
652 | Radtke T, Liszewska N, Horodyska K, et al. Cooking together: The IKEA effect on family vegetable intake. Br J Health Psychol. 2019;24:896-912. doi:10.1111/bjhp.12385. | Age of some participants at I/E
653 | Rafiroiu AC, Anderson EP, Sargent RG, et al. Dietary practices of South Carolina adolescents and their parents. American Journal of Health Behavior. 2002;26:200-212. doi:10.5993/ajhb.26.3.5. | Study design
654 | Rangelov N, Della Bella S, Marques-Vidal P, et al. Does additional support provided through e-mail or SMS in a Web-based Social Marketing program improve children’s food consumption? A Randomized Controlled Trial. Nutr J. 2018;17:24. doi:10.1186/s12937-018-0334-1. | Intervention/exposure; Comparator
655 | Ranstrom BB. Taking Steps Together: a family centered, lifestyle education and behavioral modification program for overweight and obese children and their families. North Dakota State University. 2009. | Publication status
656 | Rathi N, Riddell L, Worsley A. Indian adolescents’ perceptions of the home food environment. BMC Public Health. 2018;18:169. doi:10.1186/s12889-018-5083-8. | Study design; Country
657 | Rauber F, Hoffman DJ, Vitolo MR. Diet quality from pre-school to school age in Brazilian children: a 4-year follow-up in a randomised control study. Br J Nutr. 2014;111:499-505. doi:10.1017/s0007114513002857. | Intervention/exposure
658 | Rauber F, Martins CA, Azeredo CM, et al. Eating context and ultraprocessed food consumption among UK adolescents. Br J Nutr. 2022;127:112-122. doi:10.1017/s0007114521000854. | Study design
659 | Ray C, Figueiredo R, Pajulahti R, et al. Effects of the Preschool-Based Family-Involving DAGIS Intervention on Family Environment: A Cluster Randomised Trial. Nutrients.2020;12(11):3387. Published 2020 Nov 4. doi:10.3390/nu12113387 | Outcome
660 | Ray C, Figuereido R, Vepsäläinen H, et al. Effects of the Preschool-Based Family-Involving DAGIS Intervention Program on Children’s Energy Balance-Related Behaviors and Self-Regulation Skills: A Clustered Randomized Controlled Trial. Nutrients. 2020;12(9):2599. Published 2020 Aug 26. doi:10.3390/nu12092599 | Intervention/exposure
661 | Ray C, Roos E. Family characteristics predicting favourable changes in 10 and 11-year-old children’s lifestyle-related health behaviours during an 18-month follow-up. Appetite. 2012;58:326-32. doi:10.1016/j.appet.2011.10.009. | Age of some participants at I/E
662 | Ray C, Suominen S, Roos E. The role of parents’ sense of coherence in irregular meal pattern and food intake pattern of children aged 10-11 in Finland. J Epidemiol Community Health. 2009;63:1005-9. doi:10.1136/jech.2008.085100. | Study design
663 | Raynor HA, Van Walleghen EL, Osterholt KM, et al. The relationship between child and parent food hedonics and parent and child food group intake in children with overweight/obesity. J Am Diet Assoc. 2011;111:425-30. doi:10.1016/j.jada.2010.12.013. | Study design
664 | Reagan R, Woodruff SJ, Seabrook JA, Gilliland J. A randomized control trial of a Canadian-based school food program on the home food environment. Health Promot Int. 2022;37(3):daac087. doi:10.1093/heapro/daac087 | Outcome
665 | Reese AC, Burgos-Gil R, Cleary SD, et al. Use of a Water Filter at Home Reduces Sugary Drink Consumption among Parents and Infants/Toddlers in a Predominantly Hispanic Community: Results from the Water Up!@ Home Intervention Trial. J Acad Nutr Diet. 2023;123:41-51. doi:10.1016/j.jand.2022.06.006. | Intervention/exposure
666 | Reinaerts E, de Nooijer J, Candel M, et al. Explaining school children’s fruit and vegetable consumption: the contributions of availability, accessibility, exposure, parental consumption and habit in addition to psychosocial factors. Appetite. 2007;48:248-58. doi:10.1016/j.appet.2006.09.007. | Study design
667 | Reinaerts E, de Nooijer J, Candel M, et al. Increasing children’s fruit and vegetable consumption: distribution or a multicomponent programme?. Public Health Nutr. 2007;10:939-47. doi:10.1017/s1368980007665495. | Intervention/exposure
668 | Reinaerts E, de Nooijer J, de Vries NK. Parental versus child reporting of fruit and vegetable consumption. Int J Behav Nutr Phys Act. 2007;4:33. doi:10.1186/1479-5868-4- 33. | Study design
669 | Remington A, Añez E, Croker H, et al. Increasing food acceptance in the home setting: a randomized controlled trial of parent-administered taste exposure with incentives. Am J Clin Nutr. 2012;95:72-7. doi:10.3945/ajcn.111.024596. | Intervention/exposure; Outcome
670 | Renzaho AM, Dau A, Cyril S, et al. The influence of family functioning on the consumption of unhealthy foods and beverages among 1- to 12-y-old children in Victoria, Australia. Nutrition. 2014;30:1028-33. doi:10.1016/j.nut.2014.02.006. | Study design
671 | Resiak M, Walentukiewicz A, Łysak-Radomska A, et al. Determinants of overweight in the population of parents of school-age children. Int J Occup Med Environ Health. 2019;32:677–693. doi:10.13075/ijomeh.1896.01455. | Study design
672 | Rice EL, Klein WMP. Interactions among perceived norms and attitudes about health-related behaviors in U.S. adolescents. Health Psychol. 2019;38:268-275. doi:10.1037/hea0000722. | Study design
673 | Ritchie LD, Whaley SE, Spector P, et al. Favorable impact of nutrition education on California WIC families. J Nutr Educ Behav. 2010;42:S2-10. doi:10.1016/j.jneb.2010.02.014. | Study design; Intervention/exposure
674 | Roberts L, Marx JM, Musher-Eizenman DR. Using food as a reward: An examination of parental reward practices. Appetite. 2018;120:318-326. doi:10.1016/j.appet.2017.09.024. | Study design; Outcome
675 | Roberts-Gray C, Briley ME, Ranjit N, et al. Efficacy of the Lunch is in the Bag intervention to increase parents’ packing of healthy bag lunches for young children: a cluster-randomized trial in early care and education centers. Int J Behav Nutr Phys Act. 2016;13:3. doi:10.1186/s12966-015-0326-x. | Intervention/exposure; Outcome
676 | Roberts-Gray C, Ranjit N, Sweitzer SJ, et al. Parent packs, child eats: Surprising results of Lunch is in the Bag’s efficacy trial. Appetite. 2018;121:249-262. doi:10.1016/j.appet.2017.10.033. | Intervention/exposure
677 | Robertson W, Fleming J, Kamal A, et al. Randomised controlled trial and economic evaluation of the ‘Families for Health’ programme to reduce obesity in children. Arch Dis Child. 2017;102:416-426. doi:10.1136/archdischild-2016-311514. | Intervention/exposure
678 | Robertson W, Fleming J, Kamal A, et al. Randomised controlled trial evaluating the effectiveness and cost-effectiveness of ‘Families for Health’, a family-based childhood obesity treatment intervention delivered in a community setting for ages 6 to 11 years. Health Technol Assess. 2017;21:1-180. doi:10.3310/hta21010. | Age of some participants at I/E
679 | Robertson W, Friede T, Blissett J, et al. Pilot of “Families for Health”: community-based family intervention for obesity. Arch Dis Child. 2008;93:921-6. doi:10.1136/adc.2008.139162. | Study design
680 | Robertson W, Thorogood M, Inglis N, et al. Two-year follow-up of the ‘Families for Health’ programme for the treatment of childhood obesity. Child Care Health Dev. 2012;38:229-36. doi:10.1111/j.1365-2214.2011.01237.x. | Study design
681 | Robinson-O’Brien R, Neumark-Sztainer D, Hannan PJ, et al. Fruits and vegetables at home: child and parent perceptions. J Nutr Educ Behav. 2009;41:360-4. doi:10.1016/j.jneb.2008.08.003. | Study design
682 | Robson SM, Stough CO, Stark LJ. The impact of a pilot cooking intervention for parent-child dyads on the consumption of foods prepared away from home. Appetite. 2016;99:177-184. doi:10.1016/j.appet.2016.01.021. | Study design; Outcome
683 | Robson SM, Ziegler ML, McCullough MB, et al. Changes in diet quality and home food environment in preschool children following weight management. Int J Behav Nutr Phys Act. 2019;16:16. doi:10.1186/s12966-019-0777-6. | Intervention/exposure
684 | Rodenburg G, Kremers SP, Oenema A, et al. Associations of parental feeding styles with child snacking behaviour and weight in the context of general parenting. Public Health Nutr. 2014;17:960-9. doi:10.1017/s1368980013000712. | Age of some participants at I/E
685 | Rodgers RF, Hazzard VM, Franko DL, et al. Intuitive Eating among Parents: Associations with the Home Food and Meal Environment. J Acad Nutr Diet. 2022;122:1336-1344. doi:10.1016/j.jand.2022.01.009. | Study design
686 | Rodríguez-Arauz G, Ramírez-Esparza N. A naturalistic observational study on food interactions and indicators of healthy and unhealthy eating in White-European and Latinx families. Appetite. 2022;171:105905. doi:10.1016/j.appet.2021.105905. | Study design
687 | Røed M, Medin AC, Vik FN, et al. Effect of a Parent-Focused eHealth Intervention on Children’s Fruit, Vegetable, and Discretionary Food Intake (Food4toddlers): Randomized Controlled Trial. J Med Internet Res. 2021;23:e18311. doi:10.2196/18311. | Age of some participants at I/E
688 | Røed M, Vik FN, Hillesund ER, Lippevelde WV, Øverby NC. Associations between parental food choice motives, health-promoting feeding practices, and infants’ fruit and vegetable intakes: the Food4toddlers study. Food Nutr Res. 2020;64:10.29219/fnr.v64.3730. Published 2020 Oct 12. doi:10.29219/fnr.v64.3730 | Study design
689 | Rogers VW, Hart PH, Motyka E, et al. Impact of Let’s Go! 5-2-1-0: a community-based, multisetting childhood obesity prevention program. J Pediatr Psychol. 2013;38:1010-20. doi:10.1093/jpepsy/jst057. | Intervention/exposure
690 | Rohde JF, Larsen SC, Ängquist L, et al. Effects of the Healthy Start randomized intervention on dietary intake among obesity-prone normal-weight children. Public Health Nutr. 2017;20:2988-2997. doi:10.1017/s1368980017002026. | Intervention/exposure
691 | Rohde JF, Larsen SC, Händel MN, Olsen NJ, Stougaard M, Heitmann BL. Associations between Parental Stress and Subsequent Changes in Dietary Intake and Quality among Preschool Children Susceptible to Obesity. Int J Environ Res Public Health. 2021;18(7):3590. Published 2021 Mar 30. doi:10.3390/ijerph18073590 | Intervention/exposure
692 | Rollins BY, Stein W, Keller KL, et al. Preschoolers will drink their GREENS! Children accept, like, and drink novel smoothies containing dark green vegetables (DGVs). Appetite. 2021;162:105148. doi:10.1016/j.appet.2021.105148. | Intervention/exposure
693 | Romano KA, Heron KE. Regulatory parental feeding behaviors, emotion suppression, and emotional eating in the absence of hunger: Examining parent-adolescent dyadic associations. Appetite. 2021;167:105603. doi:10.1016/j.appet.2021.105603. | Study design
694 | Romanos-Nanclares A, Zazpe I, Santiago S, Marín L, Rico-Campà A, Martín-Calvo N. Influence of Parental Healthy-Eating Attitudes and Nutritional Knowledge on Nutritional Adequacy and Diet Quality among Preschoolers: The SENDO Project. Nutrients.2018;10(12):1875. Published 2018 Dec 3. doi:10.3390/nu10121875 | Study design
695 | Romo ML, Abril-Ulloa V. Improving Nutrition Habits and Reducing Sedentary Time Among Preschool-Aged Children in Cuenca, Ecuador: A Trial of a School-Based Intervention. Prev Chronic Dis. 2018;15:E96. doi:10.5888/pcd15.180053. | Intervention/exposure
696 | Rosal MC, Lemon SC, Borg A, et al. The Healthy Kids & Families study: Outcomes of a 24-month childhood obesity prevention intervention [published correction appears in Prev Med Rep. 2023 Jun 22;35:102295. doi: 10.1016/j.pmedr.2023.102295]. Prev Med Rep. 2022;31:102086. Published 2022 Dec 7. doi:10.1016/j.pmedr.2022.102086 | Intervention/exposure
697 | Rose CM, Birch LL, Savage JS. Dietary patterns in infancy are associated with child diet and weight outcomes at 6 years. Int J Obes (Lond). 2017;41:783-788. doi:10.1038/ijo.2017.27. | Intervention/exposure
698 | Rosenstock S, Ingalls A, Foy Cuddy R, et al. Effect of a Home-Visiting Intervention to Reduce Early Childhood Obesity Among Native American Children: A Randomized Clinical Trial. JAMA Pediatr. 2021;175:133-142. doi:10.1001/jamapediatrics.2020.3557. | Intervention/exposure
699 | Rotman SA, Fowler LA, Ray MK, et al. Family Encouragement of Healthy Eating Predicts Child Dietary Intake and Weight Loss in Family-Based Behavioral Weight-Loss Treatment. Child Obes. 2020;16:218-225. doi:10.1089/chi.2019.0119. | Study design; Intervention/exposure
700 | Rowan H, Lee M, Brown A. Differences in dietary composition between infants introduced to complementary foods using Baby-led weaning and traditional spoon feeding. J Hum Nutr Diet. 2019;32:11-20. doi:10.1111/jhn.12616. | Study design
701 | Ruzicka EB, Darling KE, Fahrenkamp AJ, et al. Familial influences on the use of controlling feeding practices with adolescents. Appetite. 2018;127:155-162. doi:10.1016/j.appet.2018.04.031. | Study design; Outcome
702 | Saelens BE, Scholz K, Walters K, et al. Two Pilot Randomized Trials To Examine Feasibility and Impact of Treated Parents as Peer Interventionists in Family-Based Pediatric Weight Management. Childhood obesity (Print). 2017;13:314-323. doi:10.1089/chi.2016.0233. | Intervention/exposure; Outcome
703 | Sagui-Henson SaraJ, Armstrong Laura Marie, Mitchell AlexisD, et al. The Effects of Parental Emotion Regulation Ability on Parenting Self-Efficacy and Child Diet. Journal of Child & Family Studies. 2020;29:2290-2302. doi:10.1007/s10826-020-01745-x. | Study design
704 | Sal Sema, Bektas Murat. Effectiveness of Obesity Prevention Program Developed for Secondary School Students. American Journal of Health Education. 2022;53:45-55. doi:10.1080/19325037.2021.2001774. | Intervention/exposure; Outcome
705 | Salafia EHB, Gondoli DM, Corning AF, et al. Psychological Distress as a Mediator of the Relation Between Perceived Maternal Parenting and Normative Maladaptive Eating Among Adolescent Girls. Journal of Counseling Psychology. 2007;54:434-446. doi:10.1037/0022-0167.54.4.434. | Intervention/exposure; Outcome
706 | Sallinen T, Viitasalo A, Lintu N, et al. The effects of an 8-year individualised lifestyle intervention on food consumption and nutrient intake from childhood to adolescence: the PANIC Study. J Nutr Sci. 2022;11:e40. doi:10.1017/jns.2022.13. | Study design; Intervention/exposure
707 | Samady W, Warren C, Bilaver LA, Zaslavsky J, Jiang J, Gupta R. Early Peanut Introduction Awareness, Beliefs, and Practices Among Parents and Caregivers. Pediatrics. 2023;152(2):e2022059376. doi:10.1542/peds.2022-059376 | Study design
708 | Sandvik P, Ek A, Eli K, et al. Picky eating in an obesity intervention for preschool-aged children - what role does it play, and does the measurement instrument matter?. Int J Behav Nutr Phys Act. 2019;16:76. doi:10.1186/s12966-019-0845-y. | Intervention/exposure; Outcome
709 | Sandvik P, Kuronen S, Reijs Richards H, et al. Associations of preschoolers’ dietary patterns with eating behaviors and parental feeding practices at a 12-month follow-up of obesity treatment. Appetite. 2022;168:105724. doi:10.1016/j.appet.2021.105724. | Intervention/exposure; Outcome
710 | Sanjeevi N, Lipsky LM, Siega-Riz AM, et al. Associations of infant appetitive traits during milk feeding stage with age at introduction to solids and sweet food/beverage intake. Appetite. 2022;168:105669. doi:10.1016/j.appet.2021.105669. | Intervention/exposure; Outcome
711 | Sanlier N, Ulusoy HG, Kocabaş S, et al. Mediterranean Diet Adherence among Preschoolers and its Association with Parents’ Beliefs, Attitudes, and Practices. Ecol Food Nutr. 2021;60:225-243. doi:10.1080/03670244.2020.1833874. | Study design; Outcome
712 | Santaliestra-Pasías AM, Felez AP, Huybrechts I, et al. Social Environment and Food and Beverage Intake in European Adolescents: The Helena Study. J Am Nutr Assoc.2022;41:468-480. doi:10.1080/07315724.2021.1917462. | Study design
713 | Santiago-Torres M, Cui Y, Adams AK, et al. Familial and individual predictors of obesity and insulin resistance in urban Hispanic children. Pediatr Obes. 2016;11:54-60. doi:10.1111/ijpo.12020. | Study design
714 | Scarinci IC, Hansen B, Kim YI. A Cluster-Randomized Controlled Trial to Evaluate a Community-Based Healthy Eating and Nutrition Label Interpretation Intervention Among Latinx Immigrant Mothers and Their Daughters. Journal of community health. 2021;46:313-323. doi:10.1007/s10900-020-00885-x. | Intervention/exposure
715 | Scheiwe A, Hardy R, Watt RG. Four-year follow-up of a randomized controlled trial of a social support intervention on infant feeding practices. Matern Child Nutr. 2010;6:328-37. doi:10.1111/j.1740-8709.2009.00231.x. | Intervention/exposure; Outcome
716 | Schiess SA, Grote V, Scaglioni S, et al. Intake of energy providing liquids during the first year of life in five European countries. Clin Nutr. 2010;29:726-32. doi:10.1016/j.clnu.2010.04.003. | Study design; Intervention/exposure
717 | Schneider S, Mata J, Kadel P. Relations between sweetened beverage consumption and individual, interpersonal, and environmental factors: a 6-year longitudinal study in German children and adolescents. Int J Public Health. 2020;65:559-570. doi:10.1007/s00038-020-01397-0. | Intervention/exposure
718 | Schnettler B, Grunert KG, Lobos G, et al. A latent class analysis of family eating habits in families with adolescents. Appetite. 2018;129:37-48. doi:10.1016/j.appet.2018.06.035. | Study design
719 | Schnettler B, Grunert KG, Lobos G, et al. Maternal Food-Related Practices, Quality of Diet, and Well-Being: Profiles of Chilean Mother-Adolescent Dyads. J Nutr Educ Behav. 2018;50:776-787. doi:10.1016/j.jneb.2018.03.003. | Study design
720 | Schnettler B, Lobos G, Miranda-Zapata E, Denegri M, Ares G, Hueche C. Diet Quality and Satisfaction with Life, Family Life, and Food-Related Life across Families: A Cross-Sectional Pilot Study with Mother-Father-Adolescent Triads. Int J Environ Res Public Health. 2017;14(11):1313. Published 2017 Oct 29. doi:10.3390/ijerph14111313 | Study design
721 | Schnettler B, Miranda-Zapata E, Orellana L, et al. Parents’ Modeling During the COVID-19 Pandemic: Influences on Family Members’ Diet Quality and Satisfaction With-Food-Related Life in Dual-Earner Parents With Adolescent Children. Front Nutr. 2022;9:902103. doi:10.3389/fnut.2022.902103. | Study design
722 | Schreinemachers P, Baliki G, Shrestha RM, et al. Nudging children toward healthier food choices: An experiment combining school and home gardens. Glob Food Sec. 2020;26:100454. doi:10.1016/j.gfs.2020.100454. | Country
723 | Schrempft S, van Jaarsveld CH, Fisher A, et al. The Obesogenic Quality of the Home Environment: Associations with Diet, Physical Activity, TV Viewing, and BMI in Preschool Children. PLoS One. 2015;10:e0134490. doi:10.1371/journal.pone.0134490. | Study design
724 | Schrempft S, van Jaarsveld CHM, Fisher A, et al. Maternal characteristics associated with the obesogenic quality of the home environment in early childhood. Appetite. 2016;107:392-397. doi:10.1016/j.appet.2016.08.108. | Outcome
725 | Schroeder N, Rushovich B, Bartlett E, et al. Early Obesity Prevention: A Randomized Trial of a Practice-Based Intervention in 0-24-Month Infants. J Obes. 2015;2015:795859. doi:10.1155/2015/795859. | Intervention/exposure; Outcome
726 | Schuler BR, Fowler B, Rubio D, et al. Building Blocks for Healthy Children: Evaluation of a Child Care Center-Based Obesity Prevention Pilot Among Low-Income Children. J Nutr Educ Behav. 2019;51:958-966. doi:10.1016/j.jneb.2019.04.017. | Intervention/exposure
727 | Schwartz MB, Gilstad-Hayden K, Henderson KE, et al. The Relationship between Parental Behaviors and Children’s Sugary Drink Consumption Is Moderated by a Television in the Child’s Bedroom. Child Obes. 2015;11:560-8. doi:10.1089/chi.2014.0041. | Intervention/exposure
728 | Schwartz MB, O’Connell M, Henderson KE, et al. Testing Variations on Family-Style Feeding To Increase Whole Fruit and Vegetable Consumption among Preschoolers in Child Care. Child Obes. 2015;11:499-505. doi:10.1089/chi.2015.0038. | Intervention/exposure
729 | Schwartz RP, Vitolins MZ, Case LD, et al. The YMCA Healthy, Fit, and Strong Program: a community-based, family-centered, low-cost obesity prevention/treatment pilot study. Child Obes. 2012;8:577-82. doi:10.1089/chi.2012.0060. | Study design; Intervention/exposure
730 | Schwinn TM, Schinke S, Fang L, et al. A web-based, health promotion program for adolescent girls and their mothers who reside in public housing. Addict Behav. 2014;39:757-60. doi:10.1016/j.addbeh.2013.11.029. | Intervention/exposure
731 | Sdravou K, Fotoulaki M, Emmanouilidou-Fotoulaki E, et al. Feeding Problems in Typically Developing Young Children, a Population-Based Study. Children (Basel). 2021;8(5):388. Published 2021 May 13. doi:10.3390/children8050388 | Study design
732 | Seburg EM, Kunin-Batson A, Senso MM, et al. Concern about Child Weight among Parents of Children At-Risk for Obesity. Health Behav Policy Rev. 2014;1:197-208. doi:10.14485/hbpr.1.3.4. | Study design; Outcome
733 | Seiverling L, Hendy HM, Yusupova S, et al. Improvements in Children’s Feeding Behavior after Intensive Interdisciplinary Behavioral Treatment: Comparisons by Developmental and Medical Status. Behav Modif. 2020;44:891-908. doi:10.1177/0145445519865170. | Study design; Intervention/exposure; Health status
734 | Seo DC, Lee CG. Association of school nutrition policy and parental control with childhood overweight. J Sch Health. 2012;82:285-93. doi:10.1111/j.1746- 1561.2012.00699.x. | Study design; Outcome
735 | Serrano M, Torres R, Pérez CM, et al. Social environment factors, diet quality, and body weight in 12-year-old children from four public schools in Puerto Rico. P R Health Sci J. 2014;33:80-7. | Study design
736 | Sharma S, Helfman L, Albus K, et al. Feasibility and Acceptability of Brighter Bites: A Food Co-Op in Schools to Increase Access, Continuity and Education of Fruits and Vegetables Among Low-Income Populations. J Prim Prev. 2015;36:281-6. doi:10.1007/s10935-015-0395-2. | Intervention/exposure
737 | Sharma SV, Markham C, Chow J, et al. Evaluating a school-based fruit and vegetable co-op in low-income children: A quasi-experimental study. Prev Med. 2016;91:8-17. doi:10.1016/j.ypmed.2016.07.022. | Intervention/exposure
738 | Sharma SV, Rashid T, Ranjit N, et al. Effectiveness of the Lunch is in the Bag program on communication between the parent, child and child-care provider around fruits, vegetables and whole grain foods: A group-randomized controlled trial. Prev Med. 2015;81:1-8. doi:10.1016/j.ypmed.2015.07.005. | Intervention/exposure; Outcome
739 | Shashaj B, Graziani MP, Contoli B, et al. Energy Balance-Related Behaviors, Perinatal, Sociodemographic, and Parental Risk Factors Associated with Obesity in Italian Preschoolers. J Am Coll Nutr. 2016;35:362-71. doi:10.1080/07315724.2015.1070699. | Study design
740 | Shriver LH, Hamm EW, Buehler CA. Predictors of fruit and vegetable intake in low-income and racially diverse preschoolers: does parental feeding style matter?. Journal of Public Health (Germany). 2019;27:407-418. doi:10.1007/s10389-018-0976-7. | Study design
741 | Sirikulchayanonta C, Iedsee K, Shuaytong P, et al. Using food experience, multimedia and role models for promoting fruit and vegetable consumption in Bangkok kindergarten children. Nutrition & Dietetics. 2010;67:97-101. doi:10.1111/j.1747-0080.2010.01426.x. | Study design; Intervention/exposure
742 | Sitarik AR, Kerver JM, Havstad SL, et al. Infant Feeding Practices and Subsequent Dietary Patterns of School-Aged Children in a US Birth Cohort. J Acad Nutr Diet. 2021;121(6):1064-1079. doi:10.1016/j.jand.2020.08.083 | Intervention/exposure
743 | Skala K, Chuang RJ, Evans A, et al. Ethnic differences in the home food environment and parental food practices among families of low-income Hispanic and African-American preschoolers. J Immigr Minor Health. 2012;14:1014-22. doi:10.1007/s10903- 012-9575-9. | Study design; Outcome
744 | Skeer MR, Eliasziw M, Sonneville KR, et al. A new tool to capture dimensions of family dinners in relation to adolescent health and risk-related outcomes: The ‘Family Dinner Index’. Prev Med Rep. 2023;35:102318. doi:10.1016/j.pmedr.2023.102318. | Study design
745 | Skouteris H, Hill B, McCabe M, et al. A parent-based intervention to promote healthy eating and active behaviours in pre-school children: evaluation of the MEND 2-4 randomized controlled trial. Pediatr Obes. 2016;11:4-10. doi:10.1111/ijpo.12011. | Intervention/exposure
746 | Sleddens EF, Kremers SP, De Vries NK, et al. Relationship between parental feeding styles and eating behaviours of Dutch children aged 6-7. Appetite. 2010;54:30-6.doi:10.1016/j.appet.2009.09.002. | Study design
747 | Sleddens EF, Kremers SP, Stafleu A, et al. Food parenting practices and child dietary behavior. Prospective relations and the moderating role of general parenting. Appetite. 2014;79:42-50. doi:10.1016/j.appet.2014.04.004. | Age of some participants at I/E
748 | Slimmer L. A school nutrition education programme improved fruit, juice, and vegetable intake, related psychosocial behaviour, and knowledge…commentary on Baranowski T, Davis M, Resnicow K et al. Gimme 5 fruit, juice, and vegetables for fun and health: outcome evaluation. Health Edu Behav. 2000 Feb;27(1): 96-111. Evidence based nursing. 2000;77-77. | Publication status
749 | Smith AD, Fildes A, Cooke L, et al. Genetic and environmental influences on food preferences in adolescence. Am J Clin Nutr. 2016;104:446-53. doi:10.3945/ajcn.116.133983. | Intervention/exposure; Outcome
750 | Smith AD, Fildes A, Forwood S, et al. The individual environment, not the family is the most important influence on preferences for common non-alcoholic beverages in adolescence. Sci Rep. 2017;7:16822. doi:10.1038/s41598-017-17020-x. | Study design; Intervention/exposure
751 | Smith E, Sutarso T, Kaye GL. Access With Education Improves Fruit and Vegetable Intake in Preschool Children. J Nutr Educ Behav. 2020;52:145-151. doi:10.1016/j.jneb.2019.07.016. | Intervention/exposure
752 | Smith KJ, McNaughton SA, Gall SL, et al. Associations between Partnering and Parenting Transitions and Dietary Habits in Young Adults. J Acad Nutr Diet. 2017;117:1210-1221. doi:10.1016/j.jand.2016.12.008. | Intervention/exposure
753 | Smith LR, Chadwick P, Radley D, et al. Assessing the short-term outcomes of a community-based intervention for overweight and obese children: The MEND 5-7 programme. BMJ Open. 2013;3(5):e002607. Published 2013 May 3. doi:10.1136/bmjopen-2013-002607 | Intervention/exposure
754 | Smith MA, Wells MH, Scarbecz M, et al. Parents’ Preferences and Perceptions of Their Children’s Consumption of Sugar and Non-nutritive Sugar Substitutes. Pediatr Dent. 2019;41:119-128. | Study design
755 | Snoek HM, Sessink NY, Engels RC. Food choices of 4 to 6-year-old overweight and nonoverweight children while role-playing as adults. J Fam Psychol. 2010;24:779-82. doi:10.1037/a0021639. | Study design; Intervention/exposure; Outcome
756 | Soraya S, Hastuti D, Johan I. The influence of parents feeding practices, eating knowledge, and attitude on eating behavior among senior high school students in South Tangerang, Indonesia. Open Access Macedonian Journal of Medical Sciences. 2021;9:913-918. doi:10.3889/oamjms.2021.7147. | Study design
757 | Sossamon M, Miketinas D. Relationships Between Food Security, Fruit and Vegetable Availability, and Fruit and Vegetable Intake in Elementary Children and Their Parents. Curr Dev Nutr. 2020;4:285. doi:10.1093/cdn/nzaa043_136. | Study design
758 | Spears-Lanoix EC, McKyer EL, Evans A, et al. Using Family-Focused Garden, Nutrition, and Physical Activity Programs To Reduce Childhood Obesity: The Texas! Go! Eat! Grow! Pilot Study. Child Obes. 2015;11:707-14. doi:10.1089/chi.2015.0032. | Study design; Intervention/exposure
759 | Spence AC, Campbell KJ, Crawford DA, et al. Mediators of improved child diet quality following a health promotion intervention: the Melbourne InFANT Program. Int J Behav Nutr Phys Act. 2014;11:137. doi:10.1186/s12966-014-0137-5. | Study design; Outcome
760 | Spurrier NJ, Bell L, Wilson A, et al. Minimal change in children’s lifestyle behaviours and adiposity following a home-based obesity intervention: results from a pilot study. BMC Res Notes. 2016;9:26. doi:10.1186/s13104-015-1796-2. | Intervention/exposure
761 | Spyreli E, McKinley MC, Dean M. Comparing Maternal and Paternal Complementary Feeding Practices: Findings From an Online Survey. J Nutr Educ Behav. 2021;53:531- 539. doi:10.1016/j.jneb.2020.11.018. | Study design
762 | Squires S. The lean plate. For kids, more ‘go,’ fewer ‘whoa’ foods: children can learn to like healthful foods with some encouragement from their families. Los Angeles Times - Southern California Edition (Front Page). 2005;F3-F3. | Publication status
763 | Srivastava D, Zheng LR, Dev DA. Examining correlates of feeding practices among parents of preschoolers. Nutr Health. 2022;28:555-562.doi:10.1177/02601060211032886. | Study design
764 | Srivastava G, Palmer KD, Ireland KA, et al. Shape-Up and Eat Right Families Pilot Program: Feasibility of a Weight Management Shared Medical Appointment Model in African-Americans With Obesity at an Urban Academic Medical Center. Front Pediatr. 2018;6:101. doi:10.3389/fped.2018.00101. | Intervention/exposure
765 | St George SM, Wilson DK, Van Horn ML. Project SHINE: effects of a randomized family-based health promotion program on the physical activity of African American parents. J Behav Med. 2018;41:537-549. doi:10.1007/s10865-018-9926-7. | Study design; Intervention/exposure; Outcome
766 | Stephens LD, McNaughton SA, Crawford D, et al. Correlates of dietary resilience among socioeconomically disadvantaged adolescents. Eur J Clin Nutr. 2011;65:1219-32. doi:10.1038/ejcn.2011.107. | Study design
767 | Stephens LD, McNaughton SA, Crawford D, et al. Longitudinal predictors of frequent vegetable and fruit consumption among socio-economically disadvantaged Australian adolescents. Appetite. 2014;78:165-71. doi:10.1016/j.appet.2014.03.023. | Age of some participants at I/E
768 | Stephens LD, McNaughton SA, Crawford D, et al. Predictors of high-energy foods and beverages: a longitudinal study among socio-economically disadvantaged adolescents. Public Health Nutr. 2014;17:324-37. doi:10.1017/s136898001200482x. | Outcome
769 | Story M, Neumark-Sztainer D. A perspective on family meals: do they matter?. Nutrition Today. 2005;40:261-266. | Study design; Publication status
770 | Str. Familial dietary intervention in children with excess body weight and its impact on eating habits, anthropometric and biochemical parameters. Front Endocrinol (Lausanne). 2022;13:1034148. doi:10.3389/fendo.2022.1034148. | Intervention/exposure
771 | Str. The influence of maternal nutritional behavior on the nutritional behavior of children with excess body weight. Pediatr Endocrinol Diabetes Metab. 2021;27:159-169. doi:10.5114/pedm.2021.107721. | Study design; Intervention/exposure; Outcome
772 | Straker LM, Howie EK, Smith KL, et al. The impact of Curtin University’s activity, food and attitudes program on physical activity, sedentary time and fruit, vegetable and junk food consumption among overweight and obese adolescents: a waitlist controlled trial. PLoS One. 2014;9:e111954. doi:10.1371/journal.pone.0111954. | Intervention/exposure
773 | Strochlic R, Woodward-Lopez G, Hewawitharana S, et al. A Harvest of the Month Curriculum Increases Fruit and Vegetable Intake among 4th-6th Grade Students. J Sch Health. 2021;91:750-760. doi:10.1111/josh.13066. | Intervention/exposure
774 | Sud S, Tamayo NC, Faith MS, et al. Increased restrictive feeding practices are associated with reduced energy density in 4-6-year-old, multi-ethnic children at ad libitum laboratory test-meals. Appetite. 2010;55:201-207. doi:10.1016/j.appet.2010.05.089. | Study design; Outcome
775 | Suggs LS, Della Bella S, Rangelov N, et al. Is it better at home with my family? The effects of people and place on children’s eating behavior. Appetite. 2018;121:111-118. doi:10.1016/j.appet.2017.11.002. | Study design
776 | Suliga E. Parental education and living environmental influence on physical development, nutritional habits as well as level of physical activity in Polish children and adolescents. Anthropol Anz. 2010;68:53-66. doi:10.1127/0003-5548/2010/0068. | Study design
777 | Sumonja S, Novaković B. Determinants of fruit, vegetable, and dairy consumption in a sample of schoolchildren, northern Serbia, 2012. Prev Chronic Dis. 2013;10:E178. doi:10.5888/pcd10.130072. | Study design
778 | Sun Y, Fung SSW, Man PKW, et al. Promoting Fruit and Vegetable Intake in Parents: A Cluster Randomised Controlled Trial. Int J Environ Res Public Health. 2021;18(10):5206. Published 2021 May 13. doi:10.3390/ijerph18105206 | Intervention/exposure; Outcome; Comparator
779 | Supthanasup A, Yiengprugsawan VS, Kelly M, Banwell C. Social networking sites: a new source of child feeding information for parents in Thailand. Health Promot Int. 2022;37(2):daab133. doi:10.1093/heapro/daab133 | Study design
780 | Sutherland R, Brown A, Nathan N, et al. A Multicomponent mHealth-Based Intervention (SWAP IT) to Decrease the Consumption of Discretionary Foods Packed in School Lunchboxes: Type I Effectiveness-Implementation Hybrid Cluster RandomizedControlled Trial. J Med Internet Res. 2021;23:e25256. doi:10.2196/25256. | Intervention/exposure; Outcome
781 | Sutherland R, Nathan N, Brown A, et al. A randomized controlled trial to assess the potential efficacy, feasibility and acceptability of an m-health intervention targeting parents of school aged children to improve the nutritional quality of foods packed in the lunchbox ‘SWAP IT’. Int J Behav Nutr Phys Act. 2019;16:54. doi:10.1186/s12966-019- 0812-7. | Intervention/exposure
782 | Sutter C, Taylor JC, Nishina A, et al. Parental and family predictors of fruits and vegetables in elementary school children’s home-packed lunches across a school week. Appetite. 2019;133:423-432. doi:10.1016/j.appet.2018.12.003. | Study design; Outcome
783 | Sweetman C, McGowan L, Croker H, et al. Characteristics of family mealtimes affecting children’s vegetable consumption and liking. J Am Diet Assoc. 2011;111:269-73. doi:10.1016/j.jada.2010.10.050. | Study design
784 | Sweitzer SJ, Briley ME, Roberts-Gray C, et al. Lunch is in the bag: increasing fruits, vegetables, and whole grains in sack lunches of preschool-aged children. J Am Diet Assoc. 2010;110:1058-64. doi:10.1016/j.jada.2010.04.010. | Intervention/exposure; Outcome
785 | Swindle T, McBride NM, Staley A, et al. Pester Power: Examining Children’s Influence as an Active Intervention Ingredient. J Nutr Educ Behav. 2020;52:801-807. doi:10.1016/j.jneb.2020.06.002. | Intervention/exposure
786 | Switkowski KM, Aris IM, Gingras V, et al. Estimated causal effects of complementary feeding behaviors on early childhood diet quality in a US cohort. Am J Clin Nutr. 2022;115:1105-1114. doi:10.1093/ajcn/nqac003. | Age of some participants at I/E
787 | Sylvestre MP, O’Loughlin J, Gray-Donald K, et al. Association between fruit and vegetable consumption in mothers and children in low-income, urban neighborhoods. Health Educ Behav. 2007;34:723-34. doi:10.1177/1090198106290758. | Study design; Intervention/exposure
788 | Tabak RG, Morshed AB, Schwarz CD, et al. Impact of a Healthy Weight Intervention Embedded Within a National Home Visiting Program on the Home Food Environment. Front Public Health. 2018;6:178. doi:10.3389/fpubh.2018.00178. | Intervention/exposure; Outcome
789 | Tabbakh T, Freeland-Graves JH. The home environment: A mediator of nutrition knowledge and diet quality in adolescents. Appetite. 2016;105:46-52. doi:10.1016/j.appet.2016.05.002. | Study design
790 | Tak NI, Te Velde SJ, Brug J. Are positive changes in potential determinants associated with increased fruit and vegetable intakes among primary schoolchildren? Results of two intervention studies in the Netherlands: the Schoolgruiten Project and the Pro Children Study. Int J Behav Nutr Phys Act. 2008;5:21. doi:10.1186/1479-5868-5-21. | Study design; Intervention/exposure
791 | Tak NI, Te Velde SJ, Brug J. Long-term effects of the Dutch Schoolgruiten Project-- promoting fruit and vegetable consumption among primary-school children. Public Health Nutr. 2009;12:1213-23. doi:10.1017/s1368980008003777. | Intervention/exposure
792 | Tak NI, Te Velde SJ, Oenema A, et al. The association between home environmental variables and soft drink consumption among adolescents. Exploration of mediation by individual cognitions and habit strength. Appetite. 2011;56:503-10. doi:10.1016/j.appet.2011.01.013. | Study design
793 | Talvia S, Räsänen L, Lagström H, et al. Longitudinal trends in consumption of vegetables and fruit in Finnish children in an atherosclerosis prevention study (STRIP). Eur J Clin Nutr. 2006;60:172-80. doi:10.1038/sj.ejcn.1602283. | Intervention/exposure
794 | Talvia S, Räsänen L, Lagström H, et al. Parental eating attitudes and indicators of healthy eating in a longitudinal randomized dietary intervention trial (the STRIP study). Public Health Nutr. 2011;14:2065-73. doi:10.1017/s1368980011000905. | Intervention/exposure; Age of some participants at I/E
795 | Tanja TT, Outi N, Sakari S, et al. Preliminary Finnish measures of eating competence suggest association with health-promoting eating patterns and related psychobehavioral factors in 10-17 year old adolescents. Nutrients. 2015;7:3828-46. doi:10.3390/nu7053828. | Study design; Outcome
796 | Tarro S, Lahdenperä M, Junttila N, Lampimäki A, Lagström H. Parental Self-Efficacy and Child Diet Quality between Ages 2 and 5: The STEPS Study. Nutrients. 2022;14(22):4891. Published 2022 Nov 18. doi:10.3390/nu14224891 | Intervention/exposure
797 | Tartaglia J, Jancey J, Scott JA, Dhaliwal SS, Begley A. Effectiveness of a food literacy and positive feeding practices program for parents of 0 to 5 years olds in WesternAustralia. Health Promot J Austr. 2024;35(2):263-275. doi:10.1002/hpja.742 | Study design; Outcome
798 | Taverno Ross SE, Barone Gibbs B, Documet PI, et al. ANDALE Pittsburgh: results of a promotora-led, home-based intervention to promote a healthy weight in Latino preschool children. BMC Public Health. 2018;18:360. doi:10.1186/s12889-018-5266-3. | Intervention/exposure
799 | Taylor A, Wilson C, Slater A, et al. Parent- and child-reported parenting. Associations with child weight-related outcomes. Appetite. 2011;57:700-6. doi:10.1016/j.appet.2011.08.014. | Study design
800 | Taylor C, Darby H, Upton P, et al. Can a school-based intervention increase children’s fruit and vegetable consumption in the home setting?. Perspect Public Health. 2013;133:330-6. doi:10.1177/1757913913506575. | Study design; Intervention/exposure
801 | Taylor MB, Emley E, Pratt M, et al. Structure-based feeding strategies: A key component of child nutrition. Appetite. 2017;114:47-54. doi:10.1016/j.appet.2017.03.023. | Study design
802 | Taylor RW, Cox A, Knight L, et al. A Tailored Family-Based Obesity Intervention: A Randomized Trial. Pediatrics. 2015;136:281-9. doi:10.1542/peds.2015-0595. | Intervention/exposure
803 | te Velde SJ, Chin APawMJ, De Bourdeaudhuij I, et al. Parents and friends both matter: simultaneous and interactive influences of parents and friends on European schoolchildren’s energy balance-related behaviours - the ENERGY cross-sectional study. Int J Behav Nutr Phys Act. 2014;11:82. doi:10.1186/1479-5868-11-82. | Study design
804 | Te Velde SJ, Wind M, Perez-Rodrigo C, et al. Mothers’ involvement in a school-based fruit and vegetable promotion intervention is associated with increased fruit and vegetable intakes--the Pro Children study. Int J Behav Nutr Phys Act. 2008;5:48. doi:10.1186/1479-5868-5-48. | Intervention/exposure; Age of some participants at I/E
805 | Thorsteinsdottir S, Njardvik U, Bjarnason R, et al. Taste education - A food-based intervention in a school setting, focusing on children with and without neurodevelopmental disorders and their families. A randomized controlled trial. Appetite. 2021;167:105623. doi:10.1016/j.appet.2021.105623. | Intervention/exposure
806 | Thurber KA, Banwell C, Neeman T, et al. Understanding barriers to fruit and vegetable intake in the Australian Longitudinal Study of Indigenous Children: a mixed-methods approach. Public Health Nutr. 2017;20:832-847. doi:10.1017/s1368980016003013. | Study design
807 | Thurber KA, Long J, Salmon M, et al. Sugar-sweetened beverage consumption among Indigenous Australian children aged 0-3 years and association with sociodemographic, life circumstances and health factors. Public Health Nutr. 2020;23:295-308. doi:10.1017/s1368980019001812. | Study design; Intervention/exposure
808 | Tietyen Mullins J, Walters J, Najor J, et al. Evaluation of a social marketing approach to healthy, home-cooked family meals for low-income mothers of young children. Transl Behav Med. 2020;10:1312-1321. doi:10.1093/tbm/ibaa037. | Intervention/exposure
809 | Tomayko EJ, Prince RJ, Cronin KA, et al. The Healthy Children, Strong Families 2 (HCSF2) Randomized Controlled Trial Improved Healthy Behaviors in American Indian Families with Young Children. Curr Dev Nutr. 2019;3:53-62. doi:10.1093/cdn/nzy087. | Intervention/exposure
810 | Tomayko EJ, Prince RJ, Cronin KA, et al. The Healthy Children, Strong Families intervention promotes improvements in nutrition, activity and body weight in American Indian families with young children. Public Health Nutr. 2016;19:2850-9. doi:10.1017/s1368980016001014. | Intervention/exposure
811 | Totland TorunnH, Lien Nanna, Bergh IngunnH, et al. The relationship between parental education and adolescents’ soft drink intake from the age of 11–13 years, and possible mediating effects of availability and accessibility. British Journal of Nutrition. 2013;110:926-933. doi:10.1017/S0007114512005946. | Intervention/exposure
812 | Tovar A, Choumenkovitch SF, Hennessy E, et al. Low demanding parental feeding style is associated with low consumption of whole grains among children of recent immigrants. Appetite. 2015;95:211-8. doi:10.1016/j.appet.2015.06.006. | Study design
813 | Tovar A, Fox K, Gans KM, et al. Results from the Strong Families Start at Home/Familias Fuertes Comienzan en Casa: feasibility randomised control trial to improve the diet quality of low-income, predominantly Hispanic/Latinx children. Public Health Nutr. Published online January 24, 2023. doi:10.1017/S1368980023000174 | Age of some participants at I/E
814 | Tovar A, Vaughn AE, Fisher JO, et al. Modifying the Environment and Policy Assessment and Observation (EPAO) to better capture feeding practices of family childcare home providers. Public Health Nutr. 2019;22:223-234.doi:10.1017/s1368980018002665. | Study design
815 | Tripicchio GL, Anderson J. Assessment of an Online Nutrition Education Program to Improve Mealtime Practices Among Families Receiving SNAP and WIC. Am J Health Promot. 2023;37:830-834. doi:10.1177/08901171231154885. | Intervention/exposure
816 | Tripicchio GL, Kay M, Herring S, et al. Development and Preliminary Feasibility of iByte4Health: A Mobile Health (mHealth) Pediatric Obesity Prevention Intervention to Engage Parents with Low-Income of Children 2-9 Years. Nutrients. 2021;13(12):4240. Published 2021 Nov 25. doi:10.3390/nu13124240 | Study design; Intervention/exposure
817 | Trofholz A, Tate A, Fulkerson JA, et al. Description of the home food environment in Black, White, Hmong, Latino, Native American and Somali homes with 5-7-year-old children. Public Health Nutr. 2019;22:882-893. doi:10.1017/s136898001800280x. | Study design
818 | Trofholz AC, Tate A, Keithahn H, et al. Family meal characteristics in racially/ethnically diverse and immigrant/refugee households by household food security status: A mixed methods study. Appetite. 2021;157:105000. doi:10.1016/j.appet.2020.105000. | Study design; Outcome
819 | Trofholz AC, Tate AD, Draxten ML, et al. Home food environment factors associated with the presence of fruit and vegetables at dinner: A direct observational study. Appetite. 2016;96:526-532. doi:10.1016/j.appet.2015.10.019. | Study design; Outcome
820 | Trofholz AC, Tate AD, Miner MH, et al. Associations between TV viewing at family meals and the emotional atmosphere of the meal, meal healthfulness, child dietary intake, and child weight status. Appetite. 2017;108:361-366. doi:10.1016/j.appet.2016.10.018. | Study design
821 | Trude AC, Surkan PJ, Anderson Steeves E, et al. The impact of a multilevel childhood obesity prevention intervention on healthful food acquisition, preparation, and fruit and vegetable consumption on African-American adult caregivers. Public Health Nutr. 2019;22:1300-1315. doi:10.1017/s1368980018003038. | Intervention/exposure; Age of some participants at I/E
822 | Truex L, Weems M, Patton K, et al. The Relationship between the Structure of Family Meals and Overall Diet Quality among Children with Autism Spectrum Disorder (ASD) and Typically Developing (TD) Children Ages 3-11 Years. Journal of the Academy of Nutrition & Dietetics. 2016;116:A96-A96. doi:10.1016/j.jand.2016.06.350. | Publication status
823 | Tugault-Lafleur CN, De-Jongh González O, Macdonald J, et al. Efficacy of the Aim2Be Intervention in Changing Lifestyle Behaviors Among Adolescents With Overweight and Obesity: Randomized Controlled Trial. J Med Internet Res. 2023;25:e38545. doi:10.2196/38545. | Intervention/exposure
824 | Ufholz K, Salvy SJ, Feda DM, et al. Weight discordant siblings’ ability to reduce energy intake at a meal as compensation for prior energy intake from sugar-sweetened beverages (SSBs). Nutr Health. 2021;27:59-67. doi:10.1177/0260106020960990. | Intervention/exposure; Outcome
825 | Ullevig SL, Parra-Medina D, Liang Y, et al. Impact of ¡Míranos! on parent-reported home-based healthy energy balance-related behaviors in low-income Latino preschool children: a clustered randomized controlled trial. Int J Behav Nutr Phys Act. 2023;20:33. doi:10.1186/s12966-023-01427-z. | Intervention/exposure
826 | Upton Dominic, Taylor Charlotte, Upton Penney. Parental provision and children’s consumption of fruit and vegetables did not increase following the Food Dudes programme. Health Education (0965-4283). 2014;114:58-66. doi:10.1108/HE-06-2013- 0026. | Intervention/exposure
827 | Utter J, Denny S, Farrant B, et al. Feasibility of a Family Meal Intervention to Address Nutrition, Emotional Wellbeing, and Food Insecurity of Families With Adolescents. J Nutr Educ Behav. 2019;51:885-892. doi:10.1016/j.jneb.2019.03.015. | Intervention/exposure
828 | Utter J, Denny S, Robinson E, et al. Family meals among New Zealand young people: relationships with eating behaviors and body mass index. J Nutr Educ Behav. 2013;45:3- 11. doi:10.1016/j.jneb.2012.04.010. | Study design
829 | Utter J, Scragg R, Schaaf D, et al. Relationships between frequency of family meals, BMI and nutritional aspects of the home food environment among New Zealand adolescents. Int J Behav Nutr Phys Act. 2008;5:50. doi:10.1186/1479-5868-5-50. | Study design
830 | Vaarno J, Niinikoski H, Kaljonen A, et al. Mothers’ restrictive eating and food neophobia and fathers’ dietary quality are associated with breast-feeding duration and introduction of solid foods: the STEPS study. Public Health Nutr. 2015;18:1991-2000.doi:10.1017/s1368980014002663. | Intervention/exposure; Outcome
831 | Vågstrand K. Sex differences among Swedish adolescents in mother-child relationships in the intake of different food groups. Br J Nutr. 2010;103:1205-11. doi:10.1017/s0007114509992972. | Study design
832 | Valmórbida JL, Vitolo MR. Factors associated with low consumption of fruits and vegetables by preschoolers of low socio-economic level. J Pediatr (Rio J). 2014;90:464- 71. doi:10.1016/j.jped.2014.02.002. | Study design
833 | Van Allen J, Kuhl ES, Filigno SS, et al. Changes in parent motivation predicts changes in body mass index z-score (zBMI) and dietary intake among preschoolers enrolled in a family-based obesity intervention. J Pediatr Psychol. 2014;39:1028-37. doi:10.1093/jpepsy/jsu052. | Study design; Intervention/exposure
834 | van Ansem WJ, Schrijvers CT, Rodenburg G, et al. Is there an association between the home food environment, the local food shopping environment and children’s fruit and vegetable intake? Results from the Dutch INPACT study. Public Health Nutr. 2013;16:1206-14. doi:10.1017/s1368980012003461. | Study design
835 | van Ansem WJ, Schrijvers CT, Rodenburg G, et al. Maternal educational level and children’s healthy eating behaviour: role of the home food environment (cross-sectional results from the INPACT study). Int J Behav Nutr Phys Act. 2014;11:113. doi:10.1186/s12966-014-0113-0. | Study design
836 | van Ansem WJ, van Lenthe FJ, Schrijvers CT, et al. Socio-economic inequalities in children’s snack consumption and sugar-sweetened beverage consumption: the contribution of home environmental factors. Br J Nutr. 2014;112:467-76. doi:10.1017/s0007114514001007. | Study design
837 | van Assema P, Glanz K, Martens M, et al. Differences between parents’ and adolescents’ perceptions of family food rules and availability. J Nutr Educ Behav. 2007;39:84-9. doi:10.1016/j.jneb.2006.08.031. | Study design
838 | van de Gaar VM, van Grieken A, Jansen W, et al. Children’s sugar-sweetened beverages consumption: associations with family and home-related factors, differences within ethnic groups explored. BMC Public Health. 2017;17:195. doi:10.1186/s12889- 017-4095-0. | Study design
839 | van der Horst K, Ferrage A, Rytz A. Involving children in meal preparation. Effects on food intake. Appetite. 2014;79:18-24. doi:10.1016/j.appet.2014.03.030. | Age of some participants at I/E
840 | van der Velde LA, Nguyen AN, Schoufour JD, et al. Diet quality in childhood: the Generation R Study. Eur J Nutr. 2019;58:1259-1269. doi:10.1007/s00394-018-1651-z. | Intervention/exposure
841 | Van Lippevelde W, te Velde SJ, Verloigne M, et al. Associations between home- and family-related factors and fruit juice and soft drink intake among 10- to 12-year old children. The ENERGY project. Appetite. 2013;61:59-65. doi:10.1016/j.appet.2012.10.019. | Study design
842 | Van Stappen V, Cardon G, De Craemer M, et al. The effect of a cluster-randomized controlled trial on lifestyle behaviors among families at risk for developing type 2 diabetes across Europe: the Feel4Diabetes-study. Int J Behav Nutr Phys Act. 2021;18:86. doi:10.1186/s12966-021-01153-4. | Intervention/exposure
843 | Van Strien T, van Niekerk R, Ouwens MA. Perceived parental food controlling practices are related to obesogenic or leptogenic child life style behaviors. Appetite. 2009;53:151- 4. doi:10.1016/j.appet.2009.05.011. | Study design
844 | van Vliet MS, Mesman J, Schultink JM, et al. Baby’s first bites: Association between observed maternal feeding behavior and infant vegetable intake and liking. Appetite. 2021;165:105316. doi:10.1016/j.appet.2021.105316. | Study design; Outcome
845 | van Vliet MS, Schultink JM, Jager G, et al. The Baby’s First Bites RCT: Evaluating a Vegetable-Exposure and a Sensitive-Feeding Intervention in Terms of Child Health Outcomes and Maternal Feeding Behavior During Toddlerhood. J Nutr. 2022;152:386- 398. doi:10.1093/jn/nxab387. | Age of some participants at I/E
846 | Vanhala ML, Laitinen J, Kaikkonen K, et al. Parental predictors of fruit and vegetable consumption in treatment-seeking overweight children. J Hum Nutr Diet. 2011;24:47-53.doi:10.1111/j.1365-277X.2010.01133.x. | Study design
847 | Vaughn AE, Dearth-Wesley T, Tabak RG, et al. Development of a Comprehensive Assessment of Food Parenting Practices: The Home Self-Administered Tool for Environmental Assessment of Activity and Diet Family Food Practices Survey. J Acad Nutr Diet. 2017;117:214-227. doi:10.1016/j.jand.2016.07.021. | Study design
848 | Vaughn AE, Hennink-Kaminski H, Moore R, et al. Evaluating a child care-based social marketing approach for improving children’s diet and physical activity: results from the Healthy Me, Healthy We cluster-randomized controlled trial. Transl Behav Med. 2021;11:775-784. doi:10.1093/tbm/ibaa113. | Intervention/exposure; Comparator
849 | Vaughn AE, Martin CL, Ward DS. What matters most - what parents model or what parents eat?. Appetite. 2018;126:102-107. doi:10.1016/j.appet.2018.03.025. | Study design
850 | Vega-López S, Ayers S, Gonzalvez A, et al. Diet Outcomes from a Randomized Controlled Trial Assessing a Parenting Intervention Simultaneously Targeting Healthy Eating and Substance Use Prevention among Hispanic Middle-School Adolescents. Nutrients. 2023;15(17):3790. Published 2023 Aug 30. doi:10.3390/nu15173790 | Intervention/exposure
851 | Vejrup K, Lien N, Klepp KI, et al. Consumption of vegetables at dinner in a cohort of Norwegian adolescents. Appetite. 2008;51:90-6. doi:10.1016/j.appet.2007.12.004. | Age of some participants at I/E
852 | Vepsäläinen H, Mikkilä V, Erkkola M, et al. Association between home and school food environments and dietary patterns among 9-11-year-old children in 12 countries. Int J Obes Suppl. 2015;5:S66-73. doi:10.1038/ijosup.2015.22. | Study design; Outcome
853 | Verdonschot A, de Vet E, van Seeters N, et al. Caregivers’ Role in the Effectiveness of Two Dutch School-Based Nutrition Education Programmes for Children Aged 7-12 Years Old. Nutrients. 2021;13(1):140. Published 2021 Jan 1. doi:10.3390/nu13010140 | Age of some participants at I/E
854 | Vereecken C, Haerens L, De Bourdeaudhuij I, et al. The relationship between children’s home food environment and dietary patterns in childhood and adolescence. Public Health Nutr. 2010;13:1729-35. doi:10.1017/s1368980010002296. | Age of some participants at I/E
855 | Vereecken C, Huybrechts I, van Houte H, et al. Results from a dietary intervention study in preschools “Beastly Healthy at School”. Int J Public Health. 2009;54:142-9. doi:10.1007/s00038-009-8028-2. | Intervention/exposure
856 | Vereecken C, Rovner A, Maes L. Associations of parenting styles, parental feeding practices and child characteristics with young children’s fruit and vegetable consumption. Appetite. 2010;55:589-96. doi:10.1016/j.appet.2010.09.009. | Study design
857 | Vereecken CA, Keukelier E, Maes L. Influence of mother’s educational level on food parenting practices and food habits of young children. Appetite. 2004;43:93-103. doi:10.1016/j.appet.2004.04.002. | Study design
858 | Vereecken CA, Van Damme W, Maes L. Measuring attitudes, self-efficacy, and social and environmental influences on fruit and vegetable consumption of 11- and 12-year-old children: reliability and validity. J Am Diet Assoc. 2005;105:257-61. doi:10.1016/j.jada.2004.11.008. | Study design
859 | Verloigne M, Van Lippevelde W, Maes L, et al. Family- and school-based predictors of energy balance-related behaviours in children: a 6-year longitudinal study. Public Health Nutr. 2013;16:202-11. doi:10.1017/s1368980012004120. | Age of some participants at I/E
860 | Verzeletti C, Maes L, Santinello M, et al. Food-related family lifestyle associated with fruit and vegetable consumption among young adolescents in Belgium Flanders and the Veneto Region of Italy. Appetite. 2010;54:394-7. doi:10.1016/j.appet.2009.12.010. | Study design
861 | Videon TM, Manning CK. Influences on adolescent eating patterns: the importance of family meals. J Adolesc Health. 2003;32:365-73. doi:10.1016/s1054-139x(02)00711-5. | Study design
862 | Villalobos B, Miranda H, Schnettler B. Satisfaction with Food: Profiles of Two-Parent Families with Adolescent Children. Int J Environ Res Public Health. 2022;19(24):16693. Published 2022 Dec 12. doi:10.3390/ijerph192416693 | Study design
863 | Vitolo MR, Bortolini GA, Campagnolo PD, et al. Maternal dietary counseling reduces consumption of energy-dense foods among infants: a randomized controlled trial. J Nutr Educ Behav. 2012;44:140-7. doi:10.1016/j.jneb.2011.06.012. | Intervention/exposure
864 | Vitolo MR, Rauber F, Campagnolo PD, et al. Maternal dietary counseling in the first year of life is associated with a higher healthy eating index in childhood. J Nutr.2010;140:2002-7. doi:10.3945/jn.110.125211. | Intervention/exposure
865 | Vohra Jyoti, Soni Pavleen. How do Indian mothers use feeding practices with children?. Journal of Children’s Services. 2016;11:283-299. doi:10.1108/JCS-02-2016-0004. | Study design; Country
866 | Vollmer RL, Adamsons K, Foster JS, et al. Association of fathers’ feeding practices and feeding style on preschool age children’s diet quality, eating behavior and body mass index. Appetite. 2015;89:274-81. doi:10.1016/j.appet.2015.02.021. | Study design
867 | Vollmer RL, Adamsons K, Foster JS, et al. How Are Fathers’ Demographic Characteristics Related to Preschool-Age Children’s Weight and Obesity Risk Factors?. Ecol Food Nutr. 2017;56:381-392. doi:10.1080/03670244.2017.1343726. | Study design
868 | Vollmer RL, Baietto J. Practices and preferences: Exploring the relationships between food-related parenting practices and child food preferences for high fat and/or sugar foods, fruits, and vegetables. Appetite. 2017;113:134-140. doi:10.1016/j.appet.2017.02.019. | Study design; Outcome
869 | Vollmer RL. Parental feeding style changes the relationships between children’s food preferences and food parenting practices: The case for comprehensive food parenting interventions by pediatric healthcare professionals. J Spec Pediatr Nurs. 2019;24:e12230. doi:10.1111/jspn.12230. | Study design
870 | Voortman T, Kiefte-de Jong JC, Geelen A, et al. The development of a diet quality score for preschool children and its validation and determinants in the Generation R Study. J Nutr. 2015;145:306-14. doi:10.3945/jn.114.199349. | Intervention/exposure
871 | Wadhera D, Capaldi Phillips ED, Wilkie LM, et al. Perceived recollection of frequent exposure to foods in childhood is associated with adulthood liking. Appetite. 2015;89:22- 32. doi:10.1016/j.appet.2015.01.011. | Study design; Outcome; Age of some participants at I/E
872 | Wadolowska L, Slowinska MA, Pabjan-Adach K, et al. The comparison of food eating models of mothers and their daughters. Pakistan Journal of Nutrition. 2007;6:381-386. doi:10.3923/pjn.2007.381.386. | Study design; Intervention/exposure
873 | Walsh AD, Cameron AJ, Hesketh KD, et al. Associations between dietary intakes of first-time fathers and their 20-month-old children are moderated by fathers’ BMI, education and age. Br J Nutr. 2015;114:988-94. doi:10.1017/s0007114515002755. | Study design
874 | Walton K, Horton NJ, Rifas-Shiman SL, et al. Exploring the Role of Family Functioning in the Association Between Frequency of Family Dinners and Dietary Intake Among Adolescents and Young Adults. JAMA Netw Open. 2018;1:e185217. doi:10.1001/jamanetworkopen.2018.5217. | Study design
875 | Wang C, Chen Y, Hong X, et al. Reduced Consumption of Sugar-Sweetened Beverages Is Associated with Lower Body Mass Index Z-Score Gain among Chinese Schoolchildren. Nutrients. 2022;14(19):4088. Published 2022 Oct 1. doi:10.3390/nu14194088 | Study design; Intervention/exposure; Outcome
876 | Wang L, Dalton WT 3rd, Schetzina, et al. Home food environment, dietary intake, and weight among overweight and obese children in Southern Appalachia. South Med J. 2013;106:550-7. doi:10.1097/smj.0000000000000008. | Study design
877 | Wang M, Druker S, Gapinski MA, et al. The Role of Social Support vs. Modeling on Adolescents’ Diet and Physical Activity: Findings from a School-based Weight Management Trial. J Child Adolesc Behav. 2014;2(2):132. doi:10.4172/2375- 4494.1000132 | Intervention/exposure
878 | Wang ML, Otis M, Rosal MC, et al. Reducing sugary drink intake through youth empowerment: results from a pilot-site randomized study. Int J Behav Nutr Phys Act. 2019;16:58. doi:10.1186/s12966-019-0819-0. | Intervention/exposure
879 | Wang Y, Tussing L, Odoms-Young A, et al. Obesity prevention in low socioeconomic status urban African-american adolescents: study design and preliminary findings of the HEALTH-KIDS Study. Eur J Clin Nutr. 2006;60:92-103. doi:10.1038/sj.ejcn.1602272. | Intervention/exposure
880 | Wang Z, Jansen EC, Miller AL, et al. Childhood emotional and behavioral characteristics are associated with soda intake: A prospective study in Mexico City. Pediatr Obes. 2020;15:e12682. doi:10.1111/ijpo.12682. | Intervention/exposure
881 | Wardle J, Cooke LJ, Gibson EL, et al. Increasing children’s acceptance of vegetables; a randomized trial of parent-led exposure. Appetite. 2003;40:155-62. doi:10.1016/s0195-6663(02)00135-6. | Intervention/exposure
882 | Warkentin S, Mais LA, Ranganath K, et al. Controlling and less controlling feeding practices are differentially associated with child food intake and appetitive behaviors assessed in a school environment. Pediatr Obes. 2020;15:e12714. doi:10.1111/ijpo.12714. | Study design
883 | Watson A, Dumuid D, Maher C, et al. Parenting Styles and Their Associations With Children’s Body Composition, Activity Patterns, Fitness, Diet, Health, and Academic Achievement. Child Obes. 2023;19:316-331. doi:10.1089/chi.2022.0054. | Study design
884 | Watt RG, Tull KI, Hardy R, et al. Effectiveness of a social support intervention on infant feeding practices: randomised controlled trial. J Epidemiol Community Health. 2009;63:156-62. doi:10.1136/jech.2008.077115. | Intervention/exposure
885 | Watt RG. Evaluation of a peer support infant feeding intervention. Journal of dental research. 2006;85. | Publication status
886 | Watt TT, Appel L, Roberts K, et al. Sugar, stress, and the Supplemental Nutrition Assistance Program: early childhood obesity risks among a clinic-based sample of low-income Hispanics. J Community Health. 2013;38:513-20. doi:10.1007/s10900-012-9641- 1. | Study design
887 | Watts AW, Barr SI, Hanning RM, et al. The home food environment and associations with dietary intake among adolescents presenting for a lifestyle modification intervention. BMC Nutr. 2018;4:3. doi:10.1186/s40795-018-0210-6. | Study design
888 | Weatherspoon LJ, Venkatesh S, Horodynski MA, et al. Food patterns and mealtime behaviors in low-income mothers and toddlers. J Community Health Nurs. 2013;30:1-15. doi:10.1080/07370016.2013.750188. | Study design
889 | Webb HaleyJ, Zimmer-Gembeck MelanieJ, Scuffham PaulA, et al. Family stress predicts poorer dietary quality in children: Examining the role of the parent–child relationship. Infant & Child Development. 2018;27:1-1. doi:10.1002/icd.2088. | Intervention/exposure
890 | Wen LM, Xu H, Phongsavan P, et al. Twelve-month effectiveness of telephone and SMS support to mothers with children aged 2 years in reducing children’s BMI: a randomized controlled trial. Int J Obes (Lond). 2023;47:791-798. doi:10.1038/s41366-023-01311-7. | Intervention/exposure
891 | Wenrich TR, Brown JL, Wilson RT, et al. Impact of a community-based intervention on serving and intake of vegetables among low-income, rural Appalachian families. J Nutr Educ Behav. 2012;44:36-45. doi:10.1016/j.jneb.2011.04.012. | Intervention/exposure
892 | Whiteside-Mansell L, Swindle TM. Evaluation of Together We Inspire Smart Eating: pre-school fruit and vegetable consumption. Health Educ Res. 2019;34:62-71. doi:10.1093/her/cyy048. | Intervention/exposure
893 | Wieland ML, Hanza MMM, Weis JA, et al. Healthy Immigrant Families: Randomized Controlled Trial of a Family-Based Nutrition and Physical Activity Intervention. Am J Health Promot. 2018;32:473-484. doi:10.1177/0890117117733342. | Intervention/exposure
894 | Wijtzes AI, Jansen W, Jansen PW, et al. Maternal educational level and preschool children’s consumption of high-calorie snacks and sugar-containing beverages: mediation by the family food environment. Prev Med. 2013;57:607-12. doi:10.1016/j.ypmed.2013.08.014. | Study design
895 | Willemsen Y, Vacaru S, Beijers R, et al. Are adolescent diet quality and emotional eating predicted by history of maternal caregiving quality and concurrent inhibitory control?. Appetite. 2023;190:107020. doi:10.1016/j.appet.2023.107020. | Study design; Intervention/exposure; Outcome
896 | Williams A, de Vlieger N, Young M, et al. Dietary outcomes of overweight fathers and their children in the Healthy Dads, Healthy Kids community randomised controlled trial. J Hum Nutr Diet. 2018;31:523-532. doi:10.1111/jhn.12543. | Intervention/exposure
897 | Williams PA, Cates SC, Blitstein JL, et al. Evaluating the Impact of Six Supplemental Nutrition Assistance Program Education Interventions on Children’s At-Home Diets. Health Educ Behav. 2015;42:329-38. doi:10.1177/1090198114558589. | Intervention/exposure
898 | Williams PA, Cates SC, Blitstein JL, et al. Nutrition-education program improves preschoolers’ at-home diet: a group randomized trial. J Acad Nutr Diet. 2014;114:1001- 1008. doi:10.1016/j.jand.2014.01.015. | Intervention/exposure
899 | Willis TA, George J, Hunt C, et al. Combating Child Obesity: impact of HENRY on parenting and family lifestyle. Pediatr Obes. 2014;9:339-50. doi:10.1111/j.2047-6310.2013.00183.x. | Study design
900 | Willis TA, Roberts KP, Berry TM, et al. The impact of HENRY on parenting and family lifestyle: A national service evaluation of a preschool obesity prevention programme. Public Health. 2016;136:101-8. doi:10.1016/j.puhe.2016.04.006. | Age of some participants at I/E
901 | Wind M, Bjelland M, Pérez-Rodrigo C, et al. Appreciation and implementation of a school-based intervention are associated with changes in fruit and vegetable intake in 10- to 13-year old schoolchildren--the Pro Children study. Health education research. 2008;23:997-1007. doi:10.1093/her/cym078. | Intervention/exposure
902 | Wind M, de Bourdeaudhuij I, te Velde SJ, et al. Correlates of fruit and vegetable consumption among 11-year-old Belgian-Flemish and Dutch schoolchildren. J Nutr Educ Behav. 2006;38:211-21. doi:10.1016/j.jneb.2006.02.011. | Study design
903 | Wirthlin R, Linde JA, Trofholz A, et al. Associations between parent and child physical activity and eating behaviours in a diverse sample: an ecological momentary assessment study. Public Health Nutr. 2020;23:2728-2736. doi:10.1017/s136898002000052x. | Age of some participants at I/E
904 | Wong MS, Jones-Smith JC, Colantuoni E, et al. The Longitudinal Association Between Early Childhood Obesity and Fathers’ Involvement in Caregiving and Decision-Making. Obesity (Silver Spring). 2017;25:1754-1761. doi:10.1002/oby.21902. | Intervention/exposure
905 | Wood AC, Senn MK, Beltran A, et al. Vegetable parenting practices vary by feeding styles among middle class mothers of young children. Appetite. 2022;171:105850. doi:10.1016/j.appet.2021.105850. | Outcome
906 | Woodruff SJ, Hanning RM, McGoldrick K, et al. Healthy eating index-C is positively associated with family dinner frequency among students in grades 6-8 from Southern Ontario, Canada. Eur J Clin Nutr. 2010;64:454-60. doi:10.1038/ejcn.2010.14. | Study design
907 | Woodruff SJ, Hanning RM. Associations between family dinner frequency and specific food behaviors among grade six, seven, and eight students from Ontario and Nova Scotia. J Adolesc Health. 2009;44:431-6. doi:10.1016/j.jadohealth.2008.10.141. | Study design
908 | Woodruff SJ, Hanning RM. Effect of meal environment on diet quality rating. Can J Diet Pract Res. 2009;70:118-24. doi:10.3148/70.3.2009.118. | Study design
909 | Worobey H, Ostapkovich K, Yudin K, et al. Trying versus liking fruits and vegetables: correspondence between mothers and preschoolers. Ecol Food Nutr. 2010;49:87-97. doi:10.1080/03670240903433261. | Intervention/exposure
910 | Wright JA, Whiteley JA, Watson BL, et al. Tailored communications for obesity prevention in pediatric primary care: a feasibility study. Health Educ Res. 2018;33:14-25. doi:10.1093/her/cyx063. | Intervention/exposure; Outcome
911 | Wyse R, Campbell KJ, Brennan L, et al. A cluster randomised controlled trial of a telephone-based intervention targeting the home food environment of preschoolers (The Healthy Habits Trial): the effect on parent fruit and vegetable consumption. Int J Behav Nutr Phys Act. 2014;11:144. doi:10.1186/s12966-014-0144-6. | Age of some participants at I/E; Age at outcome
912 | Wyse R, Wolfenden L, Campbell E, et al. A pilot study of a telephone-based parental intervention to increase fruit and vegetable consumption in 3-5-year-old children. Public Health Nutr. 2011;14:2245-53. doi:10.1017/s1368980011001170. | Study design
913 | Wyse RJ, Jackson JK, Hammersley ML, et al. Parent Fruit and Vegetable Consumption Outcomes from the Translational ‘Time for Healthy Habits’ Trial: Secondary Outcomes from a Partially Randomized Preference Trial. Int J Environ Res Public Health. 2022;19(10):6165. Published 2022 May 19. doi:10.3390/ijerph19106165 | Outcome
914 | Xiang C, Zhang Y, Yong C, et al. Association between Parents’ Perceptions of Preschool Children’s Weight, Feeding Practices and Children’s Dietary Patterns: A Cross-Sectional Study in China. Nutrients. 2021;13(11):3767. Published 2021 Oct 25. doi:10.3390/nu13113767 | Study design
915 | Xu L, Odum M, Rogers CR, et al. Association Between Family/Neighborhood Cancer Risk Factors and Adolescent Dietary Behaviors: A Parent-Adolescent Dyadic Analysis. Am J Lifestyle Med. 2022;16:622-632. doi:10.1177/1559827620949215. | Study design
916 | Yang Hwa-Mi, Choo Jina. Effects of a parent-led childhood obesity management program for socioeconomically vulnerable families: A randomised controlled trial.Collegian. 2023;30:424-432. doi:10.1016/j.colegn.2022.12.002. | Age of some participants at I/E
917 | Yee AndrewZH, Lwin MayO, Ho ShirleyS. Promoting Healthier Eating via Parental Communication: Development and Validation of the Active and Restrictive Parental Guidance Questionnaire (PARQ). Health Communication. 2021;36:1514-1526. doi:10.1080/10410236.2020.1773696. | Study design
918 | Yee AZH, Lwin MO, Lau J. Parental Guidance and Children’s Healthy Food Consumption: Integrating the Theory of Planned Behavior with Interpersonal Communication Antecedents. J Health Commun. 2019;24:183-194. doi:10.1080/10810730.2019.1593552. | Study design
919 | Yip PS, Chan VW, Lee QK, et al. Diet quality and eating behavioural patterns in preschool children in Hong Kong. Asia Pac J Clin Nutr. 2017;26:298-307. doi:10.6133/apjcn.122015.09. | Study design
920 | Ystrom E, Barker M, Vollrath ME. Impact of mothers’ negative affectivity, parental locus of control and child-feeding practices on dietary patterns of 3-year-old children: the MoBa Cohort Study. Matern Child Nutr. 2012;8:103-14. doi:10.1111/j.1740-8709.2010.00257.x. | Study design; Intervention/exposure
921 | Yuan WL, Rigal N, Monnery-Patris S, et al. Early determinants of food liking among 5y-old children: a longitudinal study from the EDEN mother-child cohort. Int J Behav Nutr Phys Act. 2016;13:20. doi:10.1186/s12966-016-0342-5. | Outcome
922 | Yuhas M, Brock DP, Ritterband LM, et al. Retention and engagement of rural caregivers of adolescents in a short message service intervention to reduce sugar-sweetened beverage intake. Digit Health. 2023;9:20552076231160324. doi:10.1177/20552076231160324. | Study design; Intervention/exposure
923 | Yung TK, Lee A, Ho MM, et al. Maternal influences on fruit and vegetable consumption of schoolchildren: case study in Hong Kong. Matern Child Nutr. 2010;6:190-8. doi:10.1111/j.1740-8709.2009.00198.x. | Study design
924 | Zabinski MF, Daly T, Norman GJ, et al. Psychosocial correlates of fruit, vegetable, and dietary fat intake among adolescent boys and girls. J Am Diet Assoc. 2006;106:814-21. doi:10.1016/j.jada.2006.03.014. | Study design
925 | Zafar TA, Alkazemi D. Correlates of food intake and mealtime behaviors among Kuwaiti adolescents. Int J Adolesc Med Health. 2021;34:19-30. doi:10.1515/ijamh-2021-0005. | Study design
926 | Zahid A, Davey C, Reicks M. Beverage Intake among Children: Associations with Parent and Home-Related Factors. Int J Environ Res Public Health. 2017;14(8):929. Published 2017 Aug 18. doi:10.3390/ijerph14080929 | Study design
927 | Zahid A, Reicks M. A Newsletter/Text Message Intervention Promoting Beverage-Related Parenting Practices: Pilot Test Results. Health Promot Pract. 2019;20:897-904. doi:10.1177/1524839918779381. | Study design
928 | Zahid A, Reicks M. Gain-Framed Messages Were Related to Higher Motivation Scores for Sugar-Sweetened Beverage Parenting Practices than Loss-Framed Messages. Nutrients. 2018;10(5):625. Published 2018 May 16. doi:10.3390/nu10050625 | Intervention/exposure
929 | Zarnowiecki DM, Parletta N, Dollman J. The role of socio-economic position as a moderator of children’s healthy food intake. Br J Nutr. 2014;112:830-40. doi:10.1017/s0007114514001354. | Study design
930 | Zarychta K, Banik A, Kulis E, et al. Parental and Child Self-Efficacy Explaining Food Intake through Self-Regulation: A Dyadic Prospective Study. Appl Psychol Health Well Being. 2021;13:174-194. doi:10.1111/aphw.12225. | Intervention/exposure
931 | Zarychta K, Mullan B, Luszczynska A. It doesn’t matter what they say, it matters how they behave: Parental influences and changes in body mass among overweight and obese adolescents. Appetite. 2016;96:47-55. doi:10.1016/j.appet.2015.08.040. | Age of some participants at I/E
932 | Zeinstra GG, Koelen MA, Kok FJ, et al. Parental child-feeding strategies in relation to Dutch children’s fruit and vegetable intake. Public Health Nutr. 2010;13:787-96. doi:10.1017/s1368980009991534. | Study design
933 | Zeinstra GG, Renes RJ, Koelen MA, et al. Offering choice and its effect on Dutch children’s liking and consumption of vegetables: a randomized controlled trial. Am J Clin Nutr. 2010;91:349-56. doi:10.3945/ajcn.2009.28529. | Intervention/exposure
934 | Zhang Y, Davey C, Larson N, et al. Influence of parenting styles in the context of adolescents’ energy balance-related behaviors: Findings from the FLASHE study. Appetite. 2019;142:104364. doi:10.1016/j.appet.2019.104364. | Study design
935 | Zhang Y, Nagao-Sato S, Baltaci A, et al. Influence of paternal general parenting on Latino early adolescents’ energy balance-related behaviours and interactions with behaviour-specific parenting practices. Public Health Nutr. 2021;24:5133-5141. doi:10.1017/s1368980021002846. | Study design
936 | Zhang Y, Reyes Peralta A, Arellano Roldan Brazys P, et al. Development of a Survey to Assess Latino Fathers’ Parenting Practices Regarding Energy Balance-Related Behaviors of Early Adolescents. Health Educ Behav. 2020;47:123-133. doi:10.1177/1090198119878769. | Study design
937 | Zhang ZT, Farris KL, Sun MC, et al. Parenting Practices, Autonomous Motivation, and Adolescent Diet Habits. J Res Adolesc. 2020;30:800-816. doi:10.1111/jora.12560. | Study design; Publication status
938 | Zhao Y, Goto K, Wolff C, et al. Relationships Between Children’s Food Consumption and Social and Cultural Capital Levels Among Latino, Hmong, and Non-Hispanic White Parents of K-2 Children. Journal of Hunger and Environmental Nutrition. 2013;8:472-489. doi:10.1080/19320248.2013.816996. | Study design; Intervention/exposure
939 | Zhong D, Gunnar MR, Kelly AS, et al. Household food insecurity and obesity risk in preschool-aged children: A three-year prospective study. Soc Sci Med. 2022;307:115176. doi:10.1016/j.socscimed.2022.115176. | Intervention/exposure; Outcome
940 | Zhou N, Cheah CSL, Li Y, et al. The Role of Maternal and Child Characteristics in Chinese Children’s Dietary Intake Across Three Groups. J Pediatr Psychol. 2018;43:503-512. doi:10.1093/jpepsy/jsx131. | Study design