# Appendix 2 Literature search strategy

## Search A

This search was first run on November 28, 2023, and then periodically run using NESR’s continuous evidence monitoring methods^*^ through January 2024.

* USDA Nutrition Evidence Systematic Review Branch. Chapter 10: Continuous Evidence Monitoring. In: USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview.

[underlined: Database: PubMed]

Provider: U.S. National Library of Medicine

Date(s) Searched: November 28, 2023 (initial search); November 28, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 2 Search for PubMed

Search # | Concept | String
#1 | Caregiver Feeding | ((“Parent-Child Relations”[MeSH] OR “Parenting”[MeSH] OR “Parents”[MeSH] OR “Legal Guardians”[Mesh] OR “Grandparents”[Mesh] OR Parent[tiab] OR Parents[tiab] OR Parental[tiab] OR parenting[tiab] OR caregiver*[tiab] OR care giver*[tiab] OR maternal[tiab] OR paternal[tiab] OR mother*[tiab] OR father*[tiab] OR guardian*[tiab] OR grandparent*[tiab] OR grandmother*[tiab] OR grandfather*[tiab] OR famil*[tiab]); AND (“Portion size”[MeSH] OR Style*[tiab] OR influence*[tiab] OR practice*[tiab] OR incentiv*[tiab] OR indulgen*[tiab] OR authorita*[tiab] OR reward*[tiab] OR control*[tiab] OR pressur*[tiab] OR restrict*[tiab] OR monitor*[tiab] OR respons*[tiab] OR sooth*[tiab] OR encourag*[tiab] OR discourage*[tiab] OR uninvolv*[tiab] OR disengage*[tiab] OR non-respons*[tiab] OR nonrespons*[tiab] OR force[tiab] OR forced[tiab] OR access*[tiab] OR availab*[tiab] OR behavior*[tiab] OR behaviour*[tiab] OR “laissez faire”[tiab] OR positive[tiab] OR “portion size”[tiab] OR “home Environment*”[tiab] OR “food Environment*”[tiab]); AND (“Feeding Behavior”[MeSH:NoExp] OR “Eating”[MeSH] OR “Breast Feeding”[Mesh] OR “Bottle Feeding”[Mesh] OR “breastfe*”[tiab] OR “bottlefe*”[tiab] OR Feed*[tiab] OR fed[tiab] OR eating[tiab] OR snacking[tiab] OR consum*[tiab] OR intak*[tiab] OR diet*[tiab] OR food*[tiab])); OR (“Family”[MeSH] AND “meals”[MeSH]) OR (“Family meal”[tiab:~2] OR “family dinner”[tiab:~2] OR “Family meals”[tiab:~2] OR “family dinners”[tiab:~2] OR “family mealtime”[tiab:~2])
#2 | Guideline Adherence | “Guideline Adherence”[Mesh] OR HEI[tiab] OR “healthy eating index”[tiab] OR “dietary guideline*”[tiab] OR “nutrition guideline*”[tiab] OR “nutritional guideline*”[tiab] OR “dietary recommendation*”[tiab] OR “dietary consumption”[tiab] OR “diet score*”[tiab] OR “diet index*”[tiab] OR “diet indices”[tiab] OR “dietary index*”[tiab] OR “dietary indices”[tiab] OR “food score*”[tiab] OR “dietary pattern*”[tiab] OR “diet pattern*”[tiab] OR “eating pattern*”[tiab] OR “food pattern*”[tiab] OR “diet quality”[tiab] OR “dietary quality”[tiab] OR “Healthy diet”[tiab]
#3 | Fruits and Vegetables | “Fruit”[MeSH:NoExp] OR “Vegetables”[MeSH] OR Fruit*[tiab] OR vegetable*[tiab] OR citrus*[tiab] OR berry[tiab] OR berries[tiab] OR “leafy green”[tiab:~3] OR “leafy greens”[tiab:~3]
#4 | Edible Grains | “Edible Grain”[MeSH] OR “whole grain*”[tiab] OR wholegrain*[tiab] OR “whole meal”[tiab] OR wholemeal[tiab] OR “whole wheat”[tiab] OR wholewheat[tiab]
#5 | Sugar Sweetened Beverages | “Sugar Sweetened Beverages”[MeSH] OR soft drink*[tiab] OR soda[tiab] OR sodas[tiab] OR ((“Dietary Sugars”[Mesh] OR sugar*[tiab]) AND (“Beverages”[Mesh:NoExp] OR beverage*[tiab] OR drink*[tiab] OR “Carbonated Beverages”[Mesh] OR “Fruit and Vegetable Juices”[Mesh] OR juice[tiab] OR juices[tiab] OR “Coffee”[Mesh] OR coffee*[tiab] OR “Tea”[Mesh] OR tea[tiab] OR teas[tiab] OR “Milk”[Mesh:NoExp] OR milk[tiab] OR “Soy Milk”[Mesh] OR soymilk[tiab] OR liquid[tiab] OR liquids[tiab]))
#6 | Children 1-19 years | “Infant”[MeSH:NoExp] OR baby[tiab] OR babies[tiab] OR “Child”[Mesh] OR child[tiab] OR children[tiab] OR childhood[tiab] OR youth[tiab] OR youths[tiab] OR “Adolescent”[Mesh] OR adolescen*[tiab] OR teen*[tiab] OR preteen*[tiab] OR preadolescen*[tiab] OR preschool*[tiab] OR “pre-school*”[tiab] OR “Pediatrics”[Mesh] OR pediatric*[tiab] OR paediatric*[tiab] OR toddler*[tiab] OR kindergarten[tiab] OR prekindergarten[tiab] OR “pre-k”[tiab] OR boy[tiab] OR boys[tiab] OR girl[tiab] OR girls[tiab] OR schoolchild*[tiab] OR elementary[tiab] OR Primary school*[tiab] OR middle school*[tiab] OR high school*[tiab] OR highschool*[tiab] OR Secondary school*[tiab] OR pubescent[tiab] OR prepubescent[tiab] OR kid[tiab] OR kids[tiab] OR early years[tiab] OR pre-primary[tiab] OR “under five”[tiab] OR “under 5”[tiab] OR “first five years”[tiab] OR “first 5 years”[tiab] OR head start[tiab] OR Underage*[tiab] OR Juvenile*[tiab] OR Minor[tiab] OR minors[tiab] OR Young adult*[tiab] OR Young man[tiab] OR young men[tiab] OR young woman[tiab] OR young women[tiab]
#7 | | #1 AND (#2 OR #3 OR #4 OR #5) AND #6
#8 | Limits | #7 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])); NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Filters applied: English, from 2000/1/1 - 3000/12/12

[underlined: Database: Embase]

Provider: Elsevier

Date(s) Searched: November 28, 2023 (initial search); November 28, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 3 Search for Embase

Search # | Concept | String
#1 | Caregiver Feeding Practices | ((‘Child Parent Relation’/exp OR ‘Parent’/exp OR ‘Legal Guardian’/exp OR ‘Grandparent’/exp OR Parent:ab,ti OR Parents:ab,ti OR Parental:ab,ti OR parenting:ab,ti OR caregiver*:ab,ti OR ‘care giver*’:ab,ti OR maternal:ab,ti OR paternal:ab,ti OR mother*:ab,ti OR father*:ab,ti OR guardian*:ab,ti OR grandparent*:ab,ti OR grandmother*:ab,ti OR grandfather*:ab,ti OR famil*:ab,ti); AND (‘Portion size’/exp OR Style*:ab,ti OR influence*:ab,ti OR practice*:ab,ti OR incentiv*:ab,ti OR indulgen*:ab,ti OR authorita*:ab,ti OR reward*:ab,ti OR control*:ab,ti OR pressur*:ab,ti OR restrict*:ab,ti OR monitor*:ab,ti OR respons*:ab,ti OR sooth*:ab,ti OR encourag*:ab,ti OR discourage*:ab,ti OR uninvolv*:ab,ti OR disengage*:ab,ti OR ‘non-respons*’:ab,ti OR nonrespons*:ab,ti OR force:ab,ti OR forced:ab,ti OR access*:ab,ti OR availab*:ab,ti OR behavior*:ab,ti OR behaviour*:ab,ti OR ‘laissez faire’:ab,ti OR positive:ab,ti OR ‘portion size’:ab,ti OR ‘home Environment*’:ab,ti OR ‘food Environment*’:ab,ti); AND (‘Feeding Behavior’/de OR ‘dietary pattern’/exp OR ‘Eating’/exp OR ‘breast feeding’/exp OR ‘bottle feeding’/exp OR breastfe*:ab,ti OR bottlefe*:ab,ti OR Feed*:ab,ti OR fed:ab,ti OR eating:ab,ti OR snacking:ab,ti OR consum*:ab,ti OR intak*:ab,ti OR diet*:ab,ti OR food*:ab,ti)); OR (‘family’/exp AND ‘meals’/exp) OR (family NEAR/3 (meal* OR dinner*)):ab,ti
#2 | Guideline Adherence | ‘healthy eating index’/exp OR HEI:ab,ti OR ‘healthy eating index’:ab,ti OR ‘dietary quality’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘nutrition guideline*’:ab,ti OR ‘nutritional guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary consumption’:ab,ti OR ‘diet score*’:ab,ti OR ‘diet index*’:ab,ti OR ‘diet indices’:ab,ti OR ‘dietary index*’:ab,ti OR ‘dietary indices’:ab,ti OR ‘food score*’:ab,ti OR ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality’:ab,ti OR ‘dietary quality’:ab,ti OR ‘Healthy diet’:ab,ti
#3 | Fruits and Vegetables | ‘Fruit’/exp OR ‘Vegetables’/exp OR Fruit*:ab,ti OR vegetable*:ab,ti OR citrus*:ab,ti OR berry:ab,ti OR berries:ab,ti OR (leafy NEAR/4 green*):ab,ti
#4 | Whole Grains | ‘food Grain’/de OR ‘whole grain’/exp OR ‘whole grain*’:ab,ti OR wholegrain*:ab,ti OR ‘whole meal’:ab,ti OR wholemeal:ab,ti OR ‘whole wheat’:ab,ti OR wholewheat:ab,ti
#5 | Sugar Sweetened Beverages | ‘Sugar Sweetened Beverages’/exp OR ‘soft drink*’:ab,ti OR soda:ab,ti OR sodas:ab,ti OR ((‘sugar intake’/exp OR sugar*:ab,ti) AND (‘Beverage’/de OR beverage*:ab,ti OR drink*:ab,ti OR ‘Carbonated Beverage’/exp OR ‘Fruit and Vegetable Juice’/exp OR juice:ab,ti OR juices:ab,ti OR ‘Coffee’/exp OR coffee*:ab,ti OR ‘Tea’/exp OR tea:ab,ti OR teas:ab,ti OR ‘Milk’/exp OR milk:ab,ti OR ‘plant based milk’/exp OR soymilk:ab,ti OR liquid:ab,ti OR liquids:ab,ti))
#6 | Children 1-9 years old | ‘child’/exp OR baby:ab,ti OR babies:ab,ti OR child:ab,ti OR children:ab,ti OR childhood:ab,ti OR youth:ab,ti OR youths:ab,ti OR ‘adolescent’/exp OR adolescen*:ab,ti OR teen*:ab,ti OR preteen*:ab,ti OR preadolescen*:ab,ti OR preschool*:ab,ti OR ‘pre-school*’:ab,ti OR ‘pediatrics’/exp OR pediatric*:ab,ti OR paediatric*:ab,ti OR toddler*:ab,ti OR kindergarten:ab,ti OR prekindergarten:ab,ti OR ‘pre-k’:ab,ti OR boy:ab,ti OR boys:ab,ti OR girl:ab,ti OR girls:ab,ti OR schoolchild*:ab,ti OR elementary:ab,ti OR ‘primary school*’:ab,ti OR ‘middle school*’:ab,ti OR ‘high and school*’:ab,ti OR highschool*:ab,ti OR ‘secondary school*’:ab,ti OR pubescent:ab,ti OR prepubescent:ab,ti OR kid:ab,ti OR kids:ab,ti OR ‘early years’:ab,ti OR ‘pre-primary’:ab,ti OR ‘under five*’:ab,ti OR ‘under 5’:ab,ti OR ‘first five years’:ab,ti OR ‘first 5 years’:ab,ti OR ‘head start’:ab,ti OR underage*:ab,ti OR juvenile*:ab,ti OR minor:ab,ti OR minors:ab,ti OR ‘young adult*’:ab,ti OR ‘young man’:ab,ti OR ‘young men’:ab,ti OR ‘young woman’:ab,ti OR ‘young women’:ab,ti
#7 | | #1 AND (#2 OR #3 OR #4 OR #5) AND #6
#8 | Limits | #7 AND ([article]/lim OR [article in press]/lim); NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)); AND [english]/lim; NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’:ab,ti OR ‘retraction notice’:ti OR ‘retracted publication’:ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR ‘practice guideline’:ti OR ‘protocol’:ti) AND [2000-2024]/py

[underlined: Database: Cochrane Central Register of Controlled Trials (CENTRAL)]

Provider: John Wiley & Sons

Date(s) Searched: November 28, 2023 (initial search); November 28, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 4 Search for Cochrane CENTRAL

Search # | Concept | String
#1 | Caregiver feeding practices | (([mh “Parent-Child Relations”] OR [mh “Parenting”] OR [mh “Legal Guardians”] OR [MH “Grandparents”] OR (Parent OR Parents OR Parental OR parenting OR caregiver* OR care giver* OR maternal OR paternal OR mother* OR father* OR guardian* OR grandparent* OR grandmother* OR grandfather* OR famil*):ti,ab,kw); AND ([MH “Portion size”] OR (Style* OR influence* OR practice* OR incentiv* OR indulgen* OR authorita* OR reward* OR control* OR pressur* OR restrict* OR monitor* OR respons* OR sooth* OR encourag* OR discourage* OR uninvolv* OR disengage* OR (non NEXT respons*) OR nonrespons* OR force OR forced OR access* OR availab* OR behavior* OR behaviour* OR “laissez faire” OR positive OR “portion size” OR (home NEXT Environment*) OR (food NEXT Environment*)):ti,ab,kw); AND ([mh ^“Feeding Behavior”] OR [mh “Eating”] OR [mh “Breast Feeding”] OR [mh “Bottle Feeding”] OR (breastfe* OR bottlefe* OR Feed* OR fed OR eating OR snacking OR consum* OR intak* OR diet* OR food*):ti,ab,kw)); OR ([mh “Family”] AND [mh “meals”]) OR (family NEAR/3 (meal* OR dinner*)):ti,ab,kw
#2 | Guideline Adherence | [mh “Guideline Adherence”] OR (HEI OR “healthy eating index” OR “dietary quality” OR “dietary guideline” OR “dietary guidelines” OR “nutrition guideline” OR “nutrition guidelines” OR “nutritional guideline” OR “nutritional guidelines” OR “dietary recommendation” OR “dietary recommendations” OR “dietary consumption” OR “diet score” OR “diet scores” OR “diet index” OR “diet indexes” OR “diet indices” OR “dietary index” OR “dietary indexes” OR “dietary indices” OR “food score” OR “food scores” OR “dietary pattern” OR “dietary patterns” OR “diet pattern” OR “diet patterns” OR “eating pattern” OR “eating patterns” OR “food pattern” OR “food patterns” OR “diet quality” OR “dietary quality” OR “healthy diet”):ti,ab,kw
#3 | Fruits and vegetables | [mh ^“Fruit”] OR [mh “Vegetables”] OR (Fruit* OR vegetable* OR citrus* OR berry OR berries OR (leafy NEAR/4 green*)):ti,ab,kw
#4 | Whole grains | [mh “Edible Grain”] OR (“whole grain” OR “whole grains” OR wholegrain* OR “whole meal” OR wholemeal OR “whole wheat” OR wholewheat):ti,ab,kw
| Sugar sweetened beverages | [mh “Sugar Sweetened Beverages”] OR “soft drink” OR “soft drinks” OR soda OR sodas OR (([mh “Dietary Sugars”] OR sugar*:ti,ab,kw) AND ([mh ^“Beverages”] OR [mh “Carbonated Beverages”] OR [mh “Fruit and Vegetable Juices”] OR [mh “Coffee”] OR [mh “Tea”] OR [mh ^“Milk”] OR [mh “Soy Milk”] OR (beverage* OR drink* OR juice OR juices OR coffee* OR tea OR teas OR milk OR soymilk OR liquid OR liquids):ti,ab,kw))
| Children 1-19 | [mh “Infant”] OR [mh “Child”] OR [mh “Adolescent”] OR [mh “Pediatrics”] OR (baby OR babies OR child OR children OR childhood OR youth OR youths OR adolescen* OR teen* OR preteen* OR preadolescen* OR preschool* OR “pre-school” OR “pre-schools” OR “pre schooler” OR “preschoolers” OR pediatric* OR paediatric* OR toddler* OR kindergarten OR prekindergarten OR “pre-k” OR boy OR boys OR girl OR girls OR schoolchild* OR elementary OR “Primary school” OR “primary schools” OR “primary schooler” OR “primary schoolers” OR “middle school” OR “middle schools” OR “middle schooler” OR “middle schoolers” OR “high school” OR “high schools” OR “high schooler” OR “high schoolers” OR highschool* OR “Secondary school” OR “secondary schools” OR “secondary schooler” OR “secondary schoolers” OR pubescent OR prepubescent OR kid OR kids OR “early years” OR “pre-primary” OR “under five” OR “under 5” OR “first five years” OR “first 5 years” OR “head start” OR Underage* OR Juvenile* OR Minor OR minors OR “Young adult” OR “young adults” OR “Young man” OR “young men” OR “young woman” OR “young women”):ti,ab,kw
| | #1 AND (#2 OR #3 OR #4 OR #5) AND #6; in Trials (Word variations have been searched); Year first published: 2000-2024; Language: English

[underlined: Database: CINAHL]

Provider: EBSCO

Date(s) Searched: November 28, 2023 (initial search); November 28, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 2000 – January 9, 2024

Table A 5 Search for CINAHL

Search # | Concept | String
#1 | Caregiver feeding practices | (((MH “Parent-Child Relations+”) OR (MH “Parenting+”) OR (MH “Parents+”) OR (MH “Guardianship, Legal”+) OR (MH “Grandparents”) OR AB (parent OR parents OR parental OR parenting OR caregiver* OR maternal OR paternal OR mother* OR father* OR guardian* OR grandparent* OR grandmother* OR grandfather* OR famil*) OR TI (parent OR parents OR parental OR parenting OR caregiver* OR maternal OR paternal OR mother* OR father* OR guardian* OR grandparent* OR grandmother* OR grandfather* OR famil*)) AND; AND ((MH “Portion size”) OR AB (Style* OR influence* OR practice* OR incentiv* OR indulgen* OR authorita* OR reward* OR control* OR pressur* OR restrict* OR monitor* OR respons* OR sooth* OR encourag* OR discourage* OR uninvolv* OR disengage* OR “non-respons*” OR nonrespons* OR force OR forced OR access* OR availab* OR behavior* OR behaviour* OR “laissez faire” OR positive OR “portion size” OR “home Environment*” OR “food Environment*”) OR TI (Style* OR influence* OR practice* OR incentiv* OR indulgen* OR authorita* OR reward* OR control* OR pressur* OR restrict* OR monitor* OR respons* OR sooth* OR encourag* OR discourage* OR uninvolv* OR disengage* OR “non-respons*” OR nonrespons* OR force OR forced OR access* OR availab* OR behavior* OR behaviour* OR “laissez faire” OR positive OR “portion size” OR “home Environment*” OR “food Environment*”)); AND ((MH “Eating Behavior”) OR (MH “Eating”) OR (MH “Breast Feeding”) OR (MH “Bottle Feeding”) OR AB (“breastfe*” OR “bottlefe*” OR Feed* OR fed OR eating OR snacking OR consum* OR intak* OR diet* OR food*) OR TI (“breastfe*” OR “bottlefe*” OR Feed* OR fed OR eating OR snacking OR consum* OR intak* OR diet* OR food*))); OR ((MH “Family”) AND (MH “Meals”)) OR (AB (family N3 (meal* OR dinner*)) OR TI (family N3 (meal* OR dinner*)))
#2 | Guideline Adherence | (MH “Nutritional Requirements+”) OR AB (HEI OR “healthy eating index” OR “dietary guideline*” OR “nutrition guideline*” OR “nutritional guideline*” OR “dietary recommendation*” OR “dietary consumption” OR “diet score*” OR “diet index*” OR “diet indices” OR “dietary index*” OR “dietary indices” OR “food score*” OR “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “Healthy diet”) OR TI (HEI OR “healthy eating index” OR “dietary guideline*” OR “nutrition guideline*” OR “nutritional guideline*” OR “dietary recommendation*” OR “dietary consumption” OR “diet score*” OR “diet index*” OR “diet indices” OR “dietary index*” OR “dietary indices” OR “food score*” OR “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “Healthy diet”)
#3 | Fruits and vegetables | (MH “Fruit+”) OR (MH “Vegetables+”) OR AB (Fruit* OR vegetable* OR citrus* OR berry OR berries OR (leafy N/4 green*)) OR TI (Fruit* OR vegetable* OR citrus* OR berry OR berries OR (leafy N/4 green*))
#4 | Whole grains | (MH “bread”) OR (MH “cereals+”) OR AB (“whole grain*” OR wholegrain* OR “whole meal” OR wholemeal OR “whole wheat” OR wholewheat) OR TI (“whole grain*” OR wholegrain* OR “whole meal” OR wholemeal OR “whole wheat” OR wholewheat)
#5 | Sugar sweetened beverages | (MH “Sweetened Beverages”) OR AB (“soft drink*” OR soda OR sodas) OR TI (“soft drink*” OR soda OR sodas) OR (((MH “Dietary Sucrose”) OR AB (sugar*) OR TI (sugar*)) AND ((MH “Beverages”) OR (MH “Carbonated Beverages”) OR (MH “Fruit Juices+”) OR (MH “Coffee”) OR (MH “Tea+”) OR (MH “Milk”) OR (MH “Soy Milk”) OR AB (beverage* OR drink* OR juice OR juices OR coffee* OR tea OR teas OR milk OR soymilk OR liquid OR liquids) OR TI (beverage* OR drink* OR juice OR juices OR coffee* OR tea OR teas OR milk OR soymilk OR liquid OR liquids)))
#6 | Children 1-19 | (MH “Child+”) OR (MH “Adolescence+”) OR (MH “Pediatrics+”) OR AB (baby OR babies OR child OR children OR childhood OR youth OR youths OR adolescen* OR teen* OR preteen* OR preadolescen* OR preschool* OR “pre-school*” OR pediatric* OR paediatric* OR toddler* OR kindergarten OR prekindergarten OR “pre-k” OR boy OR boys OR girl OR girls OR schoolchild* OR elementary OR “Primary school*” OR “middle school*” OR “high school*” OR highschool* OR “Secondary school*” OR pubescent OR prepubescent OR kid OR kids OR “early years” OR “pre-primary” OR “under five” OR “under 5” OR “first five years” OR “first 5 years” OR “head start” OR Underage* OR Juvenile* OR Minor OR minors OR “Young adult*” OR “Young man” OR “young men” OR “young woman” OR “young women”) OR TI (baby OR babies OR child OR children OR childhood OR youth OR youths OR adolescen* OR teen* OR preteen* OR preadolescen* OR preschool* OR “pre-school*” OR pediatric* OR paediatric* OR toddler* OR kindergarten OR prekindergarten OR “pre-k” OR boy OR boys OR girl OR girls OR schoolchild* OR elementary OR “Primary school*” OR “middle school*” OR “high school*” OR highschool* OR “Secondary school*” OR pubescent OR prepubescent OR kid OR kids OR “early years” OR “pre-primary” OR “under five” OR “under 5” OR “first five years” OR “first 5 years” OR “head start” OR Underage* OR Juvenile* OR Minor OR minors OR “Young adult*” OR “Young man” OR “young men” OR “young woman” OR “young women”)
#7 | | #1 AND (#2 OR #3 OR #4 OR #5) AND #6
#8 | Limits | #7 NOT ((MH “Animals+”) OR (MH “Animal Studies”)); NOT ((MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication)); Limiters - English Language, Expanders - Apply equivalent subject; Published Date: January 2000 – January 2024