# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body Mass Index
HEI: Healthy Eating Index
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
PCS: Prospective Cohort Study
RCT: Randomized Control Trial
SEP: Socioeconomic Position
SSB: Sugar Sweetened Beverages
USDA: United States Department of Agriculture