# References of the articles included in the systematic review

1 Denke MA, Adams-Huet B, Nguyen AT. Individual cholesterol variation in response to a margarine- or butter-based diet: A study in families. JAMA. Dec 6 2000;284(21):2740–7. doi:10.1001/jama.284.21.2740 11105179
2 Estevez-Gonzalez MD, Saavedra-Santana P, Betancor-Leon P. Reduction of serum cholesterol and low-density lipoprotein cholesterol levels in a juvenile population after isocaloric substitution of whole milk with a milk preparation (skimmed milk enriched with oleic acid). J Pediatr. Jan 1998;132(1):85–9. doi:10.1016/s0022-3476(98)70490-1 9470006
3 Hendrie GA, Golley RK. Changing from regular-fat to low-fat dairy foods reduces saturated fat intake but not energy intake in 4-13-y-old children. Am J Clin Nutr. May 2011;93(5):1117–27. doi:10.3945/ajcn.110.010694 21430121
4 McGovern C, Rifas-Shiman SL, Switkowski KM, . Association of cow’s milk intake in early childhood with adiposity and cardiometabolic risk in early adolescence. Am J Clin Nutr. Aug 4 2022;116(2):561–571. doi:10.1093/ajcn/nqac103 35441227
5 Villalpando S, Lara Zamudio Y, Shamah-Levy T, Mundo-Rosas V, Manzano AC, Lamadrid-Figueroa H. Substitution of whole cows’ milk with defatted milk for 4 months reduced serum total cholesterol, HDL-cholesterol and total apoB in a sample of Mexican school-age children (6-16 years of age). Br J Nutr. Sep 14 2015;114(5):788–95. doi:10.1017/S0007114515002330 26202784
6 Brassard D, Tessier-Grenier M, Allaire J, . Comparison of the impact of SFAs from cheese and butter on cardiometabolic risk factors: a randomized controlled trial. Am J Clin Nutr. Apr 2017;105(4):800–809. doi:10.3945/ajcn.116.150300 28251937
7 Chisholm A, Mann J, Sutherland W, Duncan A, Skeaff M, Frampton C. Effect on lipoprotein profile of replacing butter with margarine in a low fat diet: randomised crossover study with hypercholesterolaemic subjects. BMJ. Apr 13 1996;312(7036):931–4. doi:10.1136/bmj.312.7036.931 8616303
8 Cox C, Sutherland W, Mann J, de Jong S, Chisholm A, Skeaff M. Effects of dietary coconut oil, butter and safflower oil on plasma lipids, lipoproteins and lathosterol levels. Eur J Clin Nutr. Sep 1998;52(9):650–4. doi:10.1038/sj.ejcn.1600621 9756121
9 Crippa G, Zabzuni D, Bravi E, . Randomized, double blind placebo-controlled pilot study of the antihypertensive effects of Grana Padano D.O.P. cheese consumption in mild - moderate hypertensive subjects. Eur Rev Med Pharmacol Sci. Nov 2018;22(21):7573–7581. doi:10.26355/eurrev_201811_16299 30468507
10 Engel S, Tholstrup T. Butter increased total and LDL cholesterol compared with olive oil but resulted in higher HDL cholesterol compared with a habitual diet. Am J Clin Nutr. Aug 2015;102(2):309–15. doi:10.3945/ajcn.115.112227 26135349
11 Hjerpsted J, Leedo E, Tholstrup T. Cheese intake in large amounts lowers LDL-cholesterol concentrations compared with butter intake of equal fat content. Am J Clin Nutr. Dec 2011;94(6):1479–84. doi:10.3945/ajcn.111.022426 22030228
12 Judd JT, Baer DJ, Clevidence BA, . Effects of margarine compared with those of butter on blood lipid profiles related to cardiovascular disease risk factors in normolipemic adults fed controlled diets. Am J Clin Nutr. Oct 1998;68(4):768–77. doi:10.1093/ajcn/68.4.768 9771853
13 Karvonen HM, Tapola NS, Uusitupa MI, Sarkkinen ES. The effect of vegetable oil-based cheese on serum total and lipoprotein lipids. Eur J Clin Nutr. Nov 2002;56(11):1094–101. doi:10.1038/sj.ejcn.1601452 12428175
14 Kurowska EM, Jordan J, Spence JD, . Effects of substituting dietary soybean protein and oil for milk protein and fat in subjects with hypercholesterolemia. Clin Invest Med. Jun 1997;20(3):162–70.9189647
15 Lichtenstein AH, Ausman LM, Jalbert SM, Schaefer EJ. Effects of different forms of dietary hydrogenated fats on serum lipoprotein cholesterol levels. N Engl J Med. Jun 24 1999;340(25):1933–40. doi:10.1056/NEJM199906243402501 10379016
16 Maki KC, Rains TM, Schild AL, . Effects of low-fat dairy intake on blood pressure, endothelial function, and lipoprotein lipids in subjects with prehypertension or stage 1 hypertension. Vasc Health Risk Manag. 2013;9:369–79. doi:10.2147/VHRM.S45684 23901280
17 Meyer BJ, Larkin TA, Owen AJ, Astheimer LB, Tapsell LC, Howe PR. Limited lipid-lowering effects of regular consumption of whole soybean foods. Ann Nutr Metab. 2004;48(2):67–78. doi:10.1159/000075592 14679315
18 Mohammadi Hosseinabadi S, Nasrollahzadeh J. Effects of diets rich in ghee or olive oil on cardiometabolic risk factors in healthy adults: a two-period, crossover, randomised trial. Br J Nutr. Nov 14 2022;128(9):1720–1729. doi:10.1017/S0007114521004645 34794522
19 Morillas-Ruiz JM, Delgado-Alarcon JM, Rubio-Perez JM, Albaladejo Oton MD. The type of fat ingested at breakfast influences the plasma lipid profile of postmenopausal women. Biomed Res Int. 2014;2014:815915. doi:10.1155/2014/815915 25136625
20 Nestel PJ, Chronopulos A, Cehun M. Dairy fat in cheese raises LDL cholesterol less than that in butter in mildly hypercholesterolaemic subjects. Eur J Clin Nutr. Sep 2005;59(9):1059–63. doi:10.1038/sj.ejcn.1602211 16015270
21 Palomaki A, Pohjantahti-Maaroos H, Wallenius M, . Effects of dietary cold-pressed turnip rapeseed oil and butter on serum lipids, oxidized LDL and arterial elasticity in men with metabolic syndrome. Lipids Health Dis. Dec 1 2010;9:137. doi:10.1186/1476-511X-9-137 21122147
22 Roy SJ, Lapierre SS, Baker BD, Delfausse LA, Machin DR, Tanaka H. High dietary intake of whole milk and full-fat dairy products does not exert hypotensive effects in adults with elevated blood pressure. Nutr Res. Apr 2019;64:72–81. doi:10.1016/j.nutres.2019.01.003 30802725
23 van Meijl LE, Mensink RP. Low-fat dairy consumption reduces systolic blood pressure, but does not improve other metabolic risk parameters in overweight and obese subjects. Nutr Metab Cardiovasc Dis. May 2011;21(5):355–61. doi:10.1016/j.numecd.2009.10.008 20153619
24 Wood R, Kubena K, O’Brien B, Tseng S, Martin G. Effect of butter, mono- and polyunsaturated fatty acid-enriched butter, trans fatty acid margarine, and zero trans fatty acid margarine on serum lipids and lipoproteins in healthy men. J Lipid Res. Jan 1993;34(1):1–11.8445333
25 Alonso A, Zozaya C, Vazquez Z, Alfredo Martinez J, Martinez-Gonzalez MA. The effect of low-fat versus whole-fat dairy product intake on blood pressure and weight in young normotensive adults. J Hum Nutr Diet. Aug 2009;22(4):336–42. doi:10.1111/j.1365-277X.2009.00967.x 19486260
26 Beavers KM, Serra MC, Beavers DP, Hudson GM, Willoughby DS. The lipid-lowering effects of 4 weeks of daily soymilk or dairy milk ingestion in a postmenopausal female population. J Med Food. Jun 2010;13(3):650–6. doi:10.1089/jmf.2009.0171 20521988
27 Mohammadifard N, Hosseini M, Sajjadi F, Maghroun M, Boshtam M, Nouri F. Comparison of effects of soft margarine, blended, ghee, and unhydrogenated oil with hydrogenated oil on serum lipids: A randomized clinical trail. ARYA Atheroscler. Nov 2013;9(6):363–71.24575140
28 Nilsen R, Hostmark AT, Haug A, Skeie S. Effect of a high intake of cheese on cholesterol and metabolic syndrome: results of a randomized trial. Food Nutr Res. 2015;59:27651. doi:10.3402/fnr.v59.27651 26294049
29 Pei R, DiMarco DM, Putt KK, . Low-fat yogurt consumption reduces biomarkers of chronic inflammation and inhibits markers of endotoxin exposure in healthy premenopausal women: a randomised controlled trial. Br J Nutr. Dec 2017;118(12):1043–1051. doi:10.1017/S0007114517003038 29179781
30 Phosat C, Phosat C, Hudthagosol C, Phienluphon P, Kwanbunjan K. The effect of goat’s milk consumption on the clinical health of middle-aged adults with lactose intolerance. Malaysian Journal of Nutrition. 07/28 2022;28doi:10.31246/mjn-2021-0087
31 Raziani F, Tholstrup T, Kristensen MD, . High intake of regular-fat cheese compared with reduced-fat cheese does not affect LDL cholesterol or risk markers of the metabolic syndrome: a randomized controlled trial. Am J Clin Nutr. Oct 2016;104(4):973–981. doi:10.3945/ajcn.116.134932 27557654
32 Schlienger JL, Paillard F, Lecerf JM, . Effect on blood lipids of two daily servings of Camembert cheese. An intervention trial in mildly hypercholesterolemic subjects. Int J Food Sci Nutr. Dec 2014;65(8):1013–8. doi:10.3109/09637486.2014.945156 25095811
33 Rosqvist F, Smedman A, Lindmark-Mansson H, . Potential role of milk fat globule membrane in modulating plasma lipoproteins, gene expression, and cholesterol metabolism in humans: a randomized study. Am J Clin Nutr. Jul 2015;102(1):20–30. doi:10.3945/ajcn.115.107045 26016870
34 Bernstein AM, Sun Q, Hu FB, Stampfer MJ, Manson JE, Willett WC. Major dietary protein sources and risk of coronary heart disease in women. Circulation. Aug 31 2010;122(9):876–83. doi:10.1161/CIRCULATIONAHA.109.915165 20713902
35 Dalmeijer GW, Struijk EA, van der Schouw YT, . Dairy intake and coronary heart disease or stroke-a population-based cohort study. Int J Cardiol. Aug 10 2013;167(3):925–9. doi:10.1016/j.ijcard.2012.03.094 22483419
36 Guasch-Ferre M, Li Y, Willett WC, . Consumption of Olive Oil and Risk of Total and Cause-Specific Mortality Among U.S. Adults. J Am Coll Cardiol. Jan 18 2022;79(2):101–112. doi:10.1016/j.jacc.2021.10.041 35027106
37 Guasch-Ferre M, Liu G, Li Y, . Olive Oil Consumption and Cardiovascular Risk in U.S. Adults. J Am Coll Cardiol. Apr 21 2020;75(15):1729–1739. doi:10.1016/j.jacc.2020.02.036 32147453
38 Haring B, Gronroos N, Nettleton JA, von Ballmoos MC, Selvin E, Alonso A. Dietary protein intake and coronary heart disease in a large community based cohort: results from the Atherosclerosis Risk in Communities (ARIC) study [corrected]. PLoS One. 2014;9(10):e109552. doi:10.1371/journal.pone.0109552 25303709
39 Holmberg S, Thelin A, Stiernstrom EL. Food choices and coronary heart disease: a population based cohort study of rural Swedish men with 12 years of follow-up. Int J Environ Res Public Health. Oct 2009;6(10):2626–38. doi:10.3390/ijerph6102626 20054459
40 Jamrozik K, Broadhurst RJ, Forbes S, Hankey GJ, Anderson CS. Predictors of death and vascular events in the elderly : the Perth Community Stroke Study. Stroke. Apr 2000;31(4):863–8. doi:10.1161/01.str.31.4.863 10753989
41 Keller A, O’Reilly EJ, Malik V, . Substitution of sugar-sweetened beverages for other beverages and the risk of developing coronary heart disease: Results from the Harvard Pooling Project of Diet and Coronary Disease. Prev Med. Feb 2020;131:105970. doi:10.1016/j.ypmed.2019.105970 31883872
42 Kvist K, Laursen ASD, Overvad K, Jakobsen MU. Substitution of Milk with Whole-Fat Yogurt Products or Cheese Is Associated with a Lower Risk of Myocardial Infarction: The Danish Diet, Cancer and Health cohort. J Nutr. May 1 2020;150(5):1252–1258. doi:10.1093/jn/nxz337 31919508
43 Laursen ASD, Dahm CC, Johnsen SP, Tjonneland A, Overvad K, Jakobsen MU. Substitutions of dairy product intake and risk of stroke: a Danish cohort study. Eur J Epidemiol. Feb 2018;33(2):201–212. doi:10.1007/s10654-017-0271-x 28608185
44 Laursen ASD, Sluijs I, Boer JMA, Verschuren WMM, van der Schouw YT, Jakobsen MU. Substitutions between dairy products and risk of stroke: results from the European Investigation into Cancer and Nutrition-Netherlands (EPIC-NL) cohort. Br J Nutr. Jun 2019;121(12):1398–1404. doi:10.1017/S0007114519000564 30868976
45 Laursen ASD, Thomsen AL, Beck A, Overvad K, Jakobsen MU. Theoretical substitutions between dairy products and all-cause and cause-specific mortality. Results from the Danish diet, cancer and health cohort. Br J Nutr. May 28 2022;127(10):1557–1566. doi:10.1017/S0007114521002464 34289916
46 Liu Q, Rossouw JE, Roberts MB, . Theoretical Effects of Substituting Butter with Margarine on Risk of Cardiovascular Disease. Epidemiology. Jan 2017;28(1):145–156. doi:10.1097/EDE.0000000000000557 27648593
47 Louie JC, Flood VM, Burlutsky G, Rangan AM, Gill TP, Mitchell P. Dairy consumption and the risk of 15-year cardiovascular disease mortality in a cohort of older Australians. Nutrients. Feb 6 2013;5(2):441–54. doi:10.3390/nu5020441 23389303
48 Pacheco LS, Li Y, Rimm EB, . Avocado Consumption and Risk of Cardiovascular Disease in US Adults. J Am Heart Assoc. Apr 5 2022;11(7):e024014. doi:10.1161/JAHA.121.024014 35352568
49 Patterson E, Larsson SC, Wolk A, Akesson A. Association between dairy food consumption and risk of myocardial infarction in women differs by type of dairy food. J Nutr. Jan 2013;143(1):74–9. doi:10.3945/jn.112.166330 23173172
50 Wang S, Liu Y, Cai H, . Decreased risk of all-cause and heart-specific mortality is associated with low-fat or skimmed milk consumption compared with whole milk intake: A cohort study. Clin Nutr. Nov 2021;40(11):5568–5575. doi:10.1016/j.clnu.2021.09.012 34656953
51 Zhang Y, Zhuang P, Wu F, . Cooking oil/fat consumption and deaths from cardiometabolic diseases and other causes: prospective analysis of 521,120 individuals. BMC Med. Apr 15 2021;19(1):92. doi:10.1186/s12916-021-01961-2 33853582
52 Hu FB, Stampfer MJ, Manson JE, . Dietary saturated fats and their food sources in relation to the risk of coronary heart disease in women. Am J Clin Nutr. Dec 1999;70(6):1001–8. doi:10.1093/ajcn/70.6.1001 10584044
53 Al-Shaar L, Satija A, Wang DD, . Red meat intake and risk of coronary heart disease among US men: prospective cohort study. BMJ. Dec 2 2020;371:m4141. doi:10.1136/bmj.m4141 33268459
54 Bernstein AM, Pan A, Rexrode KM, . Dietary protein sources and the risk of stroke in men and women. Stroke. Mar 2012;43(3):637–44. doi:10.1161/STROKEAHA.111.633404 22207512
55 Ibsen DB, Levitan EB, Akesson A, Gigante B, Wolk A. The DASH diet is associated with a lower risk of heart failure: a cohort study. Eur J Prev Cardiol. May 25 2022;29(7):1114–1123. doi:10.1093/eurjpc/zwac003 34983068
56 Key TJ, Appleby PN, Bradbury KE, . Consumption of Meat, Fish, Dairy Products, and Eggs and Risk of Ischemic Heart Disease. Circulation. Jun 18 2019;139(25):2835–2845. doi:10.1161/CIRCULATIONAHA.118.038813 31006335
57 van den Brandt PA. Red meat, processed meat, and other dietary protein sources and risk of overall and cause-specific mortality in The Netherlands Cohort Study. Eur J Epidemiol. Apr 2019;34(4):351–369. doi:10.1007/s10654-019-00483-9 30673923
58 Bergeron N, Chiu S, Williams PT, S MK, Krauss RM. Effects of red meat, white meat, and nonmeat protein sources on atherogenic lipoprotein measures in the context of low compared with high saturated fat intake: a randomized controlled trial. Am J Clin Nutr. Jul 1 2019;110(1):24–33. doi:10.1093/ajcn/nqz035 31161217
59 Borgi L, Curhan GC, Willett WC, Hu FB, Satija A, Forman JP. Long-term intake of animal flesh and risk of developing hypertension in three prospective cohort studies. J Hypertens. Nov 2015;33(11):2231–8. doi:10.1097/HJH.0000000000000722 26237562
60 Bouillon K, Singh-Manoux A, Jokela M, . Decline in low-density lipoprotein cholesterol concentration: lipid-lowering drugs, diet, or physical activity? Evidence from the Whitehall II study. Heart. Jun 2011;97(11):923–30. doi:10.1136/hrt.2010.216309 21487128
61 Celada P, Olmedilla-Alonso B, Delgado-Pando G, . Coagulation, Thrombogenesis, and Insulin Resistance Markers in Increased-Cardiovascular-Risk Subjects Consuming Improved-Fat Meat Products. J Am Coll Nutr. May-Jun 2019;38(4):334–341. doi:10.1080/07315724.2018.1513345 30681939
62 Daly RM, O’Connell SL, Mundell NL, Grimes CA, Dunstan DW, Nowson CA. Protein-enriched diet, with the use of lean red meat, combined with progressive resistance training enhances lean tissue mass and muscle strength and reduces circulating IL-6 concentrations in elderly women: a cluster randomized controlled trial. Am J Clin Nutr. Apr 2014;99(4):899–910. doi:10.3945/ajcn.113.064154 24477043
63 Formica MB, Gianoudis J, Nowson CA, . Effect of lean red meat combined with a multicomponent exercise program on muscle and cognitive function in older adults: a 6-month randomized controlled trial. Am J Clin Nutr. Jul 1 2020;112(1):113–128. doi:10.1093/ajcn/nqaa104 32469398
64 Lim CGY, Tai ES, van Dam RM. Replacing dietary carbohydrates and refined grains with different alternatives and risk of cardiovascular diseases in a multi-ethnic Asian population. Am J Clin Nutr. Mar 4 2022;115(3):854–863. doi:10.1093/ajcn/nqab403 34996115
65 Liu Z, Yuan J, Wen P, . Effect of Lard or Plus Soybean Oil on Markers of Liver Function in Healthy Subjects: A Randomized Controlled-Feeding Trial. Foods. May 4 2023;12(9)doi:10.3390/foods12091894
66 Lytle JR, Price T, Crouse SF, Smith DR, Walzem RL, Smith SB. Consuming High-Fat and Low-Fat Ground Beef Depresses High-Density and Low-Density Lipoprotein Cholesterol Concentrations, and Reduces Small, Dense Low-Density Lipoprotein Particle Abundance. Nutrients. Jan 10 2023;15(2)doi:10.3390/nu15020337
67 Maki KC, Wilcox ML, Dicklin MR, . Substituting Lean Beef for Carbohydrate in a Healthy Dietary Pattern Does Not Adversely Affect the Cardiometabolic Risk Factor Profile in Men and Women at Risk for Type 2 Diabetes. J Nutr. Jul 1 2020;150(7):1824–1833. doi:10.1093/jn/nxaa116 32359153
68 Mateo-Gallego R, Perez-Calahorra S, Cenarro A, . Effect of lean red meat from lamb v. lean white meat from chicken on the serum lipid profile: a randomised, cross-over study in women. Br J Nutr. May 2012;107(10):1403–7. doi:10.1017/S0007114511004545 21902857
69 Mesana Graffe MI, Santaliestra Pasias AM, Fleta Zaragozano J, . Changes in body composition and cardiovascular risk indicators in healthy Spanish adolescents after lamb- (Ternasco de Aragon) or chicken-basic diets. Nutr Hosp. May-Jun 2013;28(3):726–33. doi:10.3305/nh.2013.28.3.6382 23848096
70 Montoro-Garcia S, Velasco-Soria A, Mora L, . Beneficial Impact of Pork Dry-Cured Ham Consumption on Blood Pressure and Cardiometabolic Markers in Individuals with Cardiovascular Risk. Nutrients. Jan 11 2022;14(2)doi:10.3390/nu14020298
71 Nielsen TB, Wurtz AML, Tjonneland A, Overvad K, Dahm CC. Substitution of unprocessed and processed red meat with poultry or fish and total and cause-specific mortality. Br J Nutr. Feb 28 2022;127(4):563–569. doi:10.1017/S0007114521001252 33829978
72 O’Connor LE, Paddon-Jones D, Wright AJ, Campbell WW. A Mediterranean-style eating pattern with lean, unprocessed red meat has cardiometabolic benefits for adults who are overweight or obese in a randomized, crossover, controlled feeding trial. Am J Clin Nutr. Jul 1 2018;108(1):33–40. doi:10.1093/ajcn/nqy075 29901710
73 Poddar KH, Ames M, Hsin-Jen C, Feeney MJ, Wang Y, Cheskin LJ. Positive effect of mushrooms substituted for meat on body weight, body composition, and health parameters. A 1-year randomized clinical trial. Appetite. Dec 2013;71:379–87. doi:10.1016/j.appet.2013.09.008 24056209
74 Razavi AC, Bazzano LA, He J, . Consumption of animal and plant foods and risk of left ventricular diastolic dysfunction: the Bogalusa Heart Study. ESC Heart Fail. Oct 2020;7(5):2700–2710. doi:10.1002/ehf2.12859 33350106
75 Rico-Campa A, Sayon-Orea C, Martinez-Gonzalez MA, . Cured ham consumption and incidence of hypertension: The “Seguimiento Universidad de Navarra” (SUN) cohort. Med Clin (Barc). Jul 10 2020;155(1):9–17. doi:10.1016/j.medcli.2019.09.019 31791802
76 Rubio JA, Rubio MA, Cabrerizo L, . Effects of pork vs veal consumption on serum lipids in healthy subjects. Nutr Hosp. Jan-Feb 2006;21(1):75–83.16562817
77 Sanchez-Muniz FJ, Canales A, Nus M, . The antioxidant status response to low-fat and walnut paste-enriched meat differs in volunteers at high cardiovascular Risk carrying different PON-1 polymorphisms. J Am Coll Nutr. Jun 2012;31(3):194–205. doi:10.1080/07315724.2012.10720027 23204156
78 Santaliestra-Pasias AM, Miguel-Berges ML, Campo MM, . Effect of the Intake of Lean Red-Meat from Beef-(Pirenaica Breed) versus Lean White-Meat on Body Composition, Fatty Acids Profile and Cardiovascular Risk Indicators: A Randomized Cross-Over Study in Healthy Young Adults. Nutrients. Sep 9 2022;14(18)doi:10.3390/nu14183724
79 Scott LW, Dunn JK, Pownall HJ, . Effects of beef and chicken consumption on plasma lipid levels in hypercholesterolemic men. Arch Intern Med. Jun 13 1994;154(11):1261–7.8203993
80 Sun Y, Liu B, Snetselaar LG, . Association of Major Dietary Protein Sources With All-Cause and Cause-Specific Mortality: Prospective Cohort Study. J Am Heart Assoc. Feb 2021;10(5):e015553. doi:10.1161/JAHA.119.015553 33624505
81 Thao U, Lajous M, Laouali N, Severi G, Boutron-Ruault MC, MacDonald CJ. Relative to processed red meat, alternative protein sources are associated with a lower risk of hypertension and diabetes in a prospective cohort of French women. Br J Nutr. Jun 14 2023;129(11):1964–1975. doi:10.1017/S0007114522002689 36045127
82 Veno SK, Bork CS, Jakobsen MU, . Substitution of Fish for Red Meat or Poultry and Risk of Ischemic Stroke. Nutrients. Nov 3 2018;10(11)doi:10.3390/nu10111648
83 Wang DD, Li Y, Nguyen XM, . Red Meat Intake and the Risk of Cardiovascular Diseases: A Prospective Cohort Study in the Million Veteran Program. J Nutr. Mar 2024;154(3):886–895. doi:10.1016/j.tjnut.2023.12.051 38163586
84 Wang M, Ma H, Song Q, . Red meat consumption and all-cause and cardiovascular mortality: results from the UK Biobank study. Eur J Nutr. Aug 2022;61(5):2543–2553. doi:10.1007/s00394-022-02807-0 35220441
85 Wurtz AM, Hansen MD, Tjonneland A, . Substitution of meat and fish with vegetables or potatoes and risk of myocardial infarction. Br J Nutr. Nov 2016;116(9):1602–1610. doi:10.1017/S0007114516003500 27774916
86 Wurtz AM, Hansen MD, Tjonneland A, . Substitutions of red meat, poultry and fish and risk of myocardial infarction. Br J Nutr. May 2016;115(9):1571–8. doi:10.1017/S0007114516000507 26949151
87 Zhong VW, Allen NB, Greenland P, . Protein foods from animal sources, incident cardiovascular disease and all-cause mortality: a substitution analysis. Int J Epidemiol. Mar 3 2021;50(1):223–233. doi:10.1093/ije/dyaa205 33411911
88 Zhu R, Fogelholm M, Jalo E, . Animal-based food choice and associations with long-term weight maintenance and metabolic health after a large and rapid weight loss: The PREVIEW study. Clin Nutr. Apr 2022;41(4):817–828. doi:10.1016/j.clnu.2022.02.002 35263691
89 Zhuang P, Wu F, Mao L, . Egg and cholesterol consumption and mortality from cardiovascular and different causes in the United States: A population-based cohort study. PLoS Med. Feb 2021;18(2):e1003508. doi:10.1371/journal.pmed.1003508 33561122
90 Baer DJ, Henderson T, Gebauer SK. Consumption of High-Oleic Soybean Oil Improves Lipid and Lipoprotein Profile in Humans Compared to a Palm Oil Blend: A Randomized Controlled Trial. Lipids. May 2021;56(3):313–325.33596340
91 Cheng C, Wang D, Xia H, . A comparative study of the effects of palm olein, cocoa butter and extra virgin olive oil on lipid profile, including low-density lipoprotein subfractions in young healthy Chinese people. Int J Food Sci Nutr. May 2019;70(3):355–366. doi:10.1080/09637486.2018.1504009 30160543
92 Chinwong S, Chinwong D, Mangklabruks A. Daily Consumption of Virgin Coconut Oil Increases High-Density Lipoprotein Cholesterol Levels in Healthy Volunteers: A Randomized Crossover Trial. Evid Based Complement Alternat Med. 2017;2017:7251562.29387131
93 Ekanayaka RA, Ekanayaka NK, Perera B, De Silva PG. Impact of a traditional dietary supplement with coconut milk and soya milk on the lipid profile in normal free living subjects. J Nutr Metab. 2013;2013:481068.24282632
94 Karupaiah T, Chuah KA, Chinna K, . Comparing effects of soybean oil- and palm olein-based mayonnaise consumption on the plasma lipid and lipoprotein profiles in human subjects: a double-blind randomized controlled trial with cross-over design. Lipids Health Dis. Aug 17 2016;15(1):131.27535127
95 Lee Y, Berryman CE, West SG, . Effects of Dark Chocolate and Almonds on Cardiovascular Risk Factors in Overweight and Obese Individuals: A Randomized Controlled-Feeding Trial. J Am Heart Assoc. Nov 29 2017;6(12)
96 Loganathan R, Nagapan G, Teng KT, . Diets enriched with palm olein, cocoa butter, and extra virgin olive oil exhibited similar lipid response: a randomized controlled study in young healthy adults. Nutr Res. Sep 2022;105:113–125. doi:10.1016/j.nutres.2022.06.011 35932536
97 Lucci P, Borrero M, Ruiz A, . Palm oil and cardiovascular disease: a randomized trial of the effects of hybrid palm oil supplementation on human plasma lipid patterns. Food Funct. Jan 2016;7(1):347–54.26488229
98 Maki KC, Hasse W, Dicklin MR, . Corn Oil Lowers Plasma Cholesterol Compared with Coconut Oil in Adults with Above-Desirable Levels of Cholesterol in a Randomized Crossover Trial. J Nutr. Oct 1 2018;148(10):1556–1563.30204921
99 Rosqvist F, Kullberg J, Stahlman M, . Overeating Saturated Fat Promotes Fatty Liver and Ceramides Compared With Polyunsaturated Fat: A Randomized Trial. J Clin Endocrinol Metab. Dec 1 2019;104(12):6207–6219. doi:10.1210/jc.2019-00160 31369090
100 Stonehouse W, Benassi-Evans B, James-Martin G, Abeywardena M. Fatty acid regio-specificity of triacylglycerol molecules may affect plasma lipid responses to dietary fats-a randomised controlled cross-over trial. Eur J Clin Nutr. Feb 2020;74(2):268–277.31227804
101 Sun G, Xia H, Yang Y, . Effects of palm olein and olive oil on serum lipids in a Chinese population: a randomized, double-blind, cross-over trial. Journal article. Asia Pacific journal of clinical nutrition. 2018;27(3):572–580.29737804
102 Sundram K, Karupaiah T, Hayes KC. Stearic acid-rich interesterified fat and trans-rich fat raise the LDL/HDL ratio and plasma glucose relative to palm olein in humans. Nutr Metab (Lond). Jan 15 2007;4:3.17224066
103 Teng KT, Voon PT, Cheng HM, Nesaretnam K. Effects of partially hydrogenated, semi-saturated, and high oleate vegetable oils on inflammatory markers and lipids. Lipids. May 2010;45(5):385–92. doi:10.1007/s11745-010-3416-1 20437207
104 van Rooijen MA, Plat J, Blom WAM, Zock PL, Mensink RP. Dietary stearic acid and palmitic acid do not differently affect ABCA1-mediated cholesterol efflux capacity in healthy men and postmenopausal women: A randomized controlled trial. Clin Nutr. Mar 2021;40(3):804–811. doi:10.1016/j.clnu.2020.08.016 32900520