# Summary of conclusion statements and grades

The 2025 Committee answered the systematic review question, “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?”, with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Children and adolescents

- A conclusion statement cannot be drawn about dairy sources of saturated fat and different comparators consumed by children and adolescents and the relationship with blood lipids or blood pressure because there is not enough evidence available. Comparators considered included similar food sources with different amounts of total fat; food sources of unsaturated fat, carbohydrate, or protein; or a different food source of saturated fat. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about meat sources of saturated fat (including red meat, processed meat, and white meat) and different comparators consumed by children and adolescents and the relationship with blood lipids or blood pressure because there is no evidence available. Comparators considered included similar food sources with different amounts of total fat; food sources of unsaturated fat, carbohydrate, or protein; or a different food source of saturated fat. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about plant sources higher in saturated fat (such as palm oil, coconut oil, or cocoa butter) and different comparators consumed by children and adolescents and the relationship with blood lipids or blood pressure because there is no evidence available. Comparators considered included similar food sources with different amounts of total fat; food sources of unsaturated fat, carbohydrate, or protein; or a different food source of saturated fat. (Grade: Grade Not Assignable)

### Adults and older adults

#### Dairy sources of saturated fat

- Substituting higher-fat dairy with lower-fat dairy by adults and older adults is not associated with a difference in risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- A conclusion statement cannot be drawn about the relationship between higher-fat dairy consumption, compared to their lower-fat versions, by adults and older adults and blood lipids, blood pressure and cardiovascular disease mortality because there is not enough evidence available. (Grade: Grade Not Assignable)
- Substituting dairy with food sources of unsaturated fatty acids by adults and older adults may be associated with a lower risk of cardiovascular disease. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- Replacing butter with plant-based oils and spreads, with predominantly unsaturated fatty acids, by adults and older adults decreases LDL-C levels but does not affect HDL-C or triglyceride levels. This conclusion statement is based on evidence graded as strong. (Grade: Strong)
- Substituting butter with plant-based oils and spreads, with predominantly unsaturated fatty acids, by adults and older adults may be associated with a decreased risk of cardiovascular disease morbidity and mortality. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- Substituting or replacing one form of dairy (including milk, yogurt, cheese, butter and buttermilk) with another form of dairy by adults and older adults is not associated with a difference in risk of cardiovascular disease. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)
- A conclusion statement cannot be drawn about the relationship between consumption of dairy compared to food sources of carbohydrates and protein by adults and older adults and risk of cardiovascular disease because of substantial concerns with consistency in the body of evidence. (Grade: Grade Not Assignable)

#### Dairy sources of saturated fat compared to meat sources of saturated fat

- Substituting processed meat and red meat with dairy by adults and older adults is associated with a lower risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)
- A conclusion statement cannot be drawn about the relationship between replacing dairy with meat consumption by adults and older adults and blood lipids, blood pressure, and cardiovascular disease mortality because there is not enough evidence available. (Grade: Grade Not Assignable)

#### Meat sources of saturated fat

- Substituting processed or unprocessed red meat with plant sources of protein (such as beans, peas, lentils, nuts, seeds, or soy) by adults and older adults is associated with lower risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)
- Substituting processed or unprocessed red meat with whole grains by adults and older adults is associated with lower risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)
- Substituting processed or unprocessed red meat with vegetables by adults and older adults is associated with lower risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)
- Substituting processed or unprocessed red meat with fish or seafood by adults and older adults may not be associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- Substituting processed or unprocessed red meat with white meat by adults and older adults is not associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)
- Replacing consumption of lean, unprocessed red meat with lean, unprocessed white meat by adults and older adults may not affect blood lipids or blood pressure. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- Substituting processed or unprocessed red meat with eggs by adults and older adults is not associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)
- Substituting white meat with plant-based foods by adults and older adults is not associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)
- Substituting white meat with fish or seafood by adults and older adults is not associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)
- A conclusion statement cannot be drawn about the effects of unprocessed meat consumption compared to plant-based foods on blood lipids or blood pressure in adults and older adults because of substantial concerns with consistency of the comparator, directness, risk of bias, and precision in the body of evidence. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between consumption of red meat with different amounts of saturated fat by adults and older adults and risk of cardiovascular disease because there is not enough evidence available. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between consumption of white meat with different amounts of saturated fat by adults and older adults and risk of cardiovascular disease because there is no evidence available. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between consumption of processed red meat compared to unprocessed red meat by adults and older adults and risk of cardiovascular disease because there is not enough evidence available. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between consumption of processed white meat compared to unprocessed white meat by adults and older adults and risk of cardiovascular disease because there is no evidence available. (Grade: Grade Not Assignable)

#### Meat sources of saturated fat compared to plant sources of saturated fat

- A conclusion statement cannot be drawn about the relationship between consumption of meat sources of saturated fat compared to plant sources of saturated fat by adults and older adults and risk of cardiovascular disease because there is no evidence available. (Grade: Grade Not Assignable)

#### Plant sources of saturated fat

- Replacing plant sources higher in saturated fat, including coconut oil, cocoa butter, and palm oil, with vegetable oils higher in unsaturated fat, by adults and older adults decreases LDL-C and has no effect on blood pressure. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)
- Replacing palm olein with vegetable oils higher in unsaturated fat by adults and older adults may not affect blood lipids. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- A conclusion statement cannot be drawn about the relationship between consumption of plant sources higher in saturated fat, compared to food sources of carbohydrate or protein, by adults and older adults and risk of cardiovascular disease because there is not enough evidence available. (Grade: Grade Not Assignable)
- A conclusion statement cannot be drawn about the relationship between consumption of plant sources higher in saturated fat, compared to a different food source of saturated fat (including dairy, meat, or another plant source of saturated fat), by adults and older adults and risk of cardiovascular disease because there is not enough evidence available. (Grade: Grade Not Assignable)

## Research recommendations

The Committee identified the following research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on food sources of saturated fat and risk of cardiovascular disease.

### Overall

1. Conduct additional U.S.-based rigorous controlled feeding studies and longitudinal observational analyses that compare specific food sources of saturated fat, especially those enrolling participants representing diverse race and/or ethnicity and throughout the lifespan.
2. Incorporate repeated dietary assessments in longitudinal studies, including the development and validation of objective measures of habitual intake, to ascertain dairy, meat, and plant-based sources of saturated fatty acids at multiple timepoints to capture individual and secular changes in consumption over time.
3. Conduct rigorous controlled trials that assess intermediate outcomes of CVD risk over longer time periods, including the ascertainment of dietary adherence over follow-up.
4. Include substitution analyses as the primary analytic framework of prospective cohort studies that compare the consumption of individual foods with risk of CVD, to improve specificity and interpretation of the findings.
5. Examine the relationship between the consumption of food sources of saturated fat and risk of CVD in populations where evidence is currently sparse, including children and adolescents, pregnant and postpartum individuals, and older adults.

### Dairy sources of saturated fat

1. Conduct trials and prospective cohort studies in children and adults comparing the effect of consuming higher fat vs. lower-fat dairy and dairy products and risk of CVD.
2. Describe dairy and dairy products more completely and precisely in prospective cohort studies. For example, include the percentage fat in dairy and dairy products, rather than just reporting as ‘low-fat’ dairy as a food category.
3. Conduct and replicate trials and prospective cohort studies that compares dairy with food sources of carbohydrates and proteins.
4. Conduct trials and prospective cohort studies that compare one form of dairy to another form (e.g., cheese vs. yogurt intake) and risk of CVD. When making these comparisons, it is critical to provide the nutritional composition, including saturated fat content, of the test foods, and conduct trials with foods of similar saturated fat content as well as ‘usual’ forms of the food that might vary in saturated fat content.
5. Assess consumption of types of plant-based milk alternatives (e.g., soy, almond, oat) separately from dairy milk to understand consumption levels and patterns by different populations, how they contribute to nutrient intakes, and their associations with health outcomes, especially cardiovascular disease intermediate health outcomes.

### Meat sources of saturated fat

1. Utilize dietary assessment tools and measures with greater distinction between types of meat (e.g., processed and unprocessed meats, red and white meats).
2. Conduct trials using commercially available, commonly consumed meats to improve generalizability.
3. Include comparisons of public health interest, such as processed vs. unprocessed meats and similar meats with varying levels of saturated fat.

### Plant sources of saturated fat

1. Conduct more trials with oils of varying levels of saturated fat, and report composition of each oil.
2. Develop dietary assessment tools that can better assess and differentiate between types of fats and oils in prospective cohort studies.

Table 30 Evidence examining the relationship between dairy consumption and risk of cardiovascular disease in children^a^

Study and Participant Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Methodological Considerations
Denke, 2000^1^; RCT-crossover, United States; Analytic N = 226 (46 families: 92 adults; 126 children); Adequately powered: NR; Study aims: To investigate individual variations in cholesterol in response to margarine or butter; Participant characteristics:; - Age: Adults: 41(4) y; Children: 12 (4); - Female: 48%; - Race and/or ethnicity: 85% White; 7% Black; 4% Hispanic American; 2% American Indian; 2% Asian American; - SEP: NR; - Adult BMI: 28.8 (6.5); - Children BMI: 19.3 (4.3); - Health Status: Overweight/Obesity; Excluded families with < 2 biological parents and < 2 biologically related children >5 y. | Intervention and Comparators:; - Butter: 50.6% SFA; - Margarine: 80% fat by weight with 38.7% cis-PUFA and 7.5 trans-fatty acids; Intervention duration: 5 wk; Other Group Differences: Significantly different: Dietary cholesterol, protein, SFA and cholesterol-raising fatty acids higher in butter intake period, fat, PUFA, trans-fat higher in margarine intake period. NS: Total energy, MUFA, CHO; Compliance: Yes, “Excellent” adherence with 88% and 83% of test fat delivered during margarine or butter being consumed; Outcome(s): LDL, HDL, TG Outcome assessment methods andtiming: Fasting blood lipids during the last 2 wks of each dietary period | [underlined: TG (mg/dL), Mean (SD)]; Butter: 68 (22); Margarine: 66 (27); Difference (95% CI): −1.8 (−6.6, 2.9), P=0.45; [underlined: LDL (mg/dL), Mean (SD)]; Butter: 104 (30); Margarine: 93 (23); Difference (95% CI): −11.2 (−14.6, −7.7), P<0.001; [underlined: HDL (mg/dL), Mean (SD)]; Butter: 48 (11); Margarine: 48 (10); Difference (95% CI): 0.15 (−1.0, 1.3), P=0.80 | Key confounders accountedfor: NA; Other covariates accounted for: Age, BMI, ad libitum LDL levels, apoE genotype, change in serum fatty acid cholesteryl ester levels nest; Limitations: Participants were not blinded; No power calculation; No analytic plan; Funding: United Soybean Board, National Association of Margarine Manufacturers, United States Public Health Service grant
Estévez-González, 1998^2^; RCT-crossover, Spain; Analytic N = 88; Adequately powered: No; Study aims: To lower serum lipid levels in children by making only one dietary change: substituting whole milk for fat-free milk enriched with oleic acid; Participant characteristics:; - Age: 3-9 y; - Female: 45%; - Race and/or ethnicity: NR; - SEP: NR; - Health Status: Healthy; Included healthy; clinically normal; no family hx of heart disease, metabolic disease, or hyperlipidemia | Intervention and Comparators:; - Whole milk; habitual intake, ~Mean: 500mL; Fat composition: 30% MUFA, 3% PUFA, 67% SFA; 107 mg/dL cholesterol; - Fat-free milk fortified with oleic acid (skimmed powered milk enriched with vegetable oils (60% olive, 20% peanut, 20% sunflower); habitual intake, ~Mean: 500mL; - Fat composition: 70% MUFA, 15% PUFA, 15% SFA; 22 mg/dL cholesterol; Intervention duration: 7 mo each; Other Group Differences: Milks varied in both SFA and MUFA/PUFA. Milks were isocaloric and both contained 32 g/L total fat; Compliance: No; though they provided milk for entire household to ensure only the designated type of milk would be available; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood lipids, assessed after each 7-month phase | [underlined: LDL (mmol/L), Mean (SD)]; Whole milk: 2.73 (0.73); Enriched milk preparation: 2.47 (0.55), p<0.001; [underlined: HDL (mmol/L), Mean (SD)]; Whole milk: 1.41 (0.33); Enriched milk preparation: 1.39 (0.28), p=NS; [underlined: TG (mmol/L), Mean (SD)]; Whole milk: 0.83 (0.39); Enriched Fat-free milk: 0.72 (0.24), p<0.01 | Key confounders accountedfor: NA; Other covariates accountedfor: None; Limitations: Inadequate information on randomization; rudimentary statistical analyses; no preregistered data analysis plan; Funding: NR
Villalpando, 2015^5^; RCT-cluster, Mexico; Analytic N = 448 (Whole milk: N=134, Partially defatted milk: N=180, Defatted milk: N=148); Adequately powered: Yes; Study aims: To compare the effect of consuming whole, partially defatted and defatted cows’ milk for 4 months on serum concentrations of blood indicators of cardiovascular risk in Mexican children and adolescents; Participant characteristics:; - Age: ~11 (2) y; 6-16 y; - Female: NR; - Race and/or ethnicity: NR but likely majority Hispanic; boarding schools are clustered in zones with a high density of indigenous population within Mexico; - SEP: NR; - BMI ~19 kg/m2; - Health Status: Healthy; Excluded those lost to follow-up and those with energy intake <30% of EER for weight, height, sex, and age, and values >p95 x 1.5 of the energy intake distribution of the sample | Intervention and Comparators:; - Partially defatted milk: cow’s milk with 2% fat; packed in foil sachets and rehydrated with purified water; 400 ml daily (200 ml at breakfast and 200 ml at dinner); - Defatted milk: cow’s milk with 0.5% fat; came in ready-to-consume liquid form in tetrabrick containers; 400 ml daily (200 ml at breakfast and 200 ml at dinner); - Whole milk: cow’s milk with 3% fat; packed in foil sachets and rehydrated with purified water; 400 ml daily (200 ml at breakfast and 200 ml at dinner); Intervention duration: 4 mo; Other Group Differences: All milk was fortified with the same micronutrient pre-mix then transferred to opaque plastic jars before serving to students; Compliance: NR; Baseline intake of study foods: All drink 2 glasses/d of whole cows’ milk at school as part of usual diet; Outcome(s): LDL, HDL, TG; Outcome assessment methods andtiming: Fasting blood collection at baseline and 4mo | [underlined: LDL (mmol/L)]; Within group: Mean (SD) at baseline, 4mo; Whole milk: 1.8 (0.47), 2.1 (0.59); Partially defatted milk: 1.8 (0.44), 2.0 (0.62); Defatted milk: 2.0 (0.52), 2.0 (0.51); Between group: change over 4mo, β (SE); Whole milk: REF; Partially defatted milk: −0.12 (0.06), P=0.014; Defatted milk: −0.28 (0.07), P=0.001; [underlined: HDL (mmol/L)]; Within group: Mean (SD) at baseline, 4mo; Whole milk: 1.3 (0.27), 1.5 (0.34); Partially defatted milk: 1.3 (0.25), 1.4 (0.30); Defatted milk: 1.5 (0.35), 1.4 (0.31); Between group: change over 4mo, β (SE); Whole milk: REF; Partially defatted milk: −0.05 (0.04), P=0.256; Defatted milk: −0.16 (0.04), P=0.001; [underlined: TG (mmol/L)]; Within group: Mean (SD) at baseline, 4mo; Whole milk: 0.87 (0.39), 1.07 (0.47); Partially defatted milk: 0.91 (0.39), 1.08 (0.47); Defatted milk: 1.00 (0.35), 1.11 (0.44); Between group: change over 4mo, β (SE); Whole milk: REF; Partially defatted milk: 0.09 (0.06), P=0.212; Defatted milk: 0.01 (0.06), P=0.435 | Key confounders accountedfor: NA; Other covariates accountedfor: None; Limitations: No preregistered data analysis plan; energy content of the milks differed but total energy intake was not significantly different between groups (Table 4); Funding: None declared
Hendrie, 2011^3^; RCT-cluster, Australia; Analytic N = 137 (Lower-fat dairy: N=76; TV time/control: N=61); Adequately powered: Yes; Study aims: To assess the effect of changing children’s dairy food choices and to evaluate the effects on children’s total and saturated fat intakes and energy and broader nutrient intakes as well as metabolic and anthropometric outcomes; 12wk active intervention, 12wk follow up; Participant characteristics:; - Age: 8.6 (3)y; 4-13y; - Female: 40%; - Race and/or ethnicity: NR; - SEP: 57% Tertiary/university degree; ~21% Full-time employment; ~40% > A$78,000 16% Overweight; 6% Obesity; BMIZ: ~0.21 (1.19); - Health Status: Healthy; Excluded participants who consumed <2svg/d regular-fat dairy, had dairy allergy or intolerance or preexisting medical condition affecting dietary intake | Intervention and Comparators:; Reduced/low-fat dairy: Milk and yogurt: reduced fat=1-2g total fat/100g, low fat ≤1g total fat/100g. Cheese: reduced fat ≤25g total fat/100g; low-fat ≤10g total fat/100g Regular-fat dairy: habitual intake of ≥2 svg/d of milk, cheese, yogurt, ice cream, custard, or dairy desserts, the majority of which were regular fat; Intervention duration: 12 wk; Other Group Differences: No other dietary guidance given; total fat, SFA, CHO differed at baseline; Compliance: Yes, indicated by change in intake and biomarker data; Baseline intake of study foods: All >2 svg/d of regular-fat dairy (inclusion criteria); Outcome(s): LDL, HDL, TG; Outcome assessment methods andtiming: Fasting blood collection at baseline, 12wk, 24wk | [underlined: LDL (mmol/L)]; Within group: Mean (SD) at baseline, 12wk, 24wk; Regular-fat dairy: 2.51 (0.69), 2.49 (0.63), 2.47 (0.60); Low-fat dairy: 2.70 (0.64), 2.59 (0.61), 2.49 (0.58); Between group: Mean difference as β (95% CI); 12wk: −0.03 (−0.20, 0.15), P=0.75; 24wk: −0.15 (−0.30, −0.01), P=0.037; [underlined: HDL (mmol/L)]; Within group: Mean (SD) at baseline, 12wk, 24wk; Regular-fat dairy: 1.46 (0.30), 1.39 (0.26), 1.43 (0.29); Low-fat dairy: 1.48 (0.29), 1.45 (0.29), 1.47 (0.27); Between group: Mean difference as β (95% CI); 12wk: 0.07 (−0.01, 0.15), P=0.10; 24wk: 0.05 (−0.03, 0.13), P=0.19; [underlined: TG (mmol/L)]; Within group: Mean (SD) at baseline, 12wk, 24wk; Regular-fat dairy: 0.74 (0.41), 0.72 (0.34), 0.69 (0.31); Low-fat dairy: 0.64 (0.24), 0.68 (0.26), 0.65 (0.33); Between group: Mean difference as β (95% CI); 12wk: −0.09 (−0.23, 0.04), P=0.17; 24wk: −0.03 (−0.16, 0.11), P=0.67 | Key confounders accountedfor: NA; Other covariates accountedfor: None; Limitations: Baseline differences between groups in sex, age total fat, SFA, CHO; no pre-registered data analysis plan; Funding: Dairy Australia LtD; National Health and Medical Research Council
McGovern, 2022^4^; PCS, United States, Project Viva; Analytic N = 796 Participant characteristics:; - Age: 3 (0.2) y; - Female: 51%; - Race and/or ethnicity: 69% White, 13% Black, 18% Other; - SEP: 74% mothers with college degree, 71% fathers with college degree, 65% with household income >$70,000 25% with BMI ≥85th%ile; - Health Status: 25% with BMI ≥85th%ile; Excluded those with missing or invalid data, those that drank primarily “other” milk or soy milk, those that did not drink milk | Exposure and Comparators:; - Low-fat milk: 1% milk or skim; - High-fat milk: whole milk or 2% milk; Exposure assessment method: FFQ at baseline completed by parents; Baseline intake of study foods: 37% drink 1% or skim milk; 63% drink whole or 2% milk; Outcome(s): HDL, TG, SBP; Outcome assessment methods and timing: Fasting blood collection and SBP assessment (average of 5 measures) at early adolescent visit (13.1±0.9y) at ~10 y follow-up | [underlined: HDL (mg/dL), β (95% CI)]; High-fat milk vs low-fat milk: Data NR (figure only), P=NS; [underlined: TG (mg/dL), β (95% CI)]; High-fat milk vs low-fat milk: Data NR (figure only), P=NS | Key confounders accounted for: Sex, age, race and/or ethnicity, socioeconomic position (parental education, marital status, neighborhood and household income), anthropometry, diet quality (modified YHEI score), total energy intake; Key confounders NOTaccounted for: Physical activity; Other covariates accounted for: milk intake frequency, parent BMI, maternal age, dietary quality during pregnancy, GWG, parity, birth weight for gestational age zscore, breastfeeding duration, early childhood sleep duration, television viewing; intakes of SSB, fiber, juice, sucrose, and other dairy; Limitations: Exposure measured at baseline only; No preregistered data analysis plan; Funding: NIH

a Abbreviations: β: beta; %tile: percentile; BMI: body mass index; BP: blood pressure; CE: cholesterol esters; CHO: carbohydrate; CI: confidence interval; d: day; DBP: diastolic blood pressure; FFQ: food frequency questionnaire; g: grams; GWG: gestational weight gain; HDL: high-density lipoprotein; hx: history; LDL: low-density lipoprotein; mg: milligram; ml: milliliter; mmol: millimoles; mo: months; MUFA: monounsaturated fatty acids; NA: not applicable; NIH: National Institutes of Health; NR: not reported; NS: non-significant; PCS: prospective cohort study; PUFA: poly-unsaturated fatty acids; RCT: Randomized controlled trial; REF: reference; SBP: systolic blood pressure; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SFA: Saturated fatty acids; SSB: sugar-sweetened beverages; TG: triglycerides; wk: week; wks: weeks; y: year; YHEI: Youth Health Eating Index

Table 31 Risk of bias for randomized controlled trials examining the relationship between dairy and/or dairy products consumed in comparison with different levels of dairy and risk of cardiovascular disease in children^a^

Article | Randomization | Identification of participants-randomization | Period and carryover effects | Deviations from the intended interventions (effect of assignment) | Deviations from the intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of reported result | Overall
Denke, 2000^1^ | HIGH | NOT APPLICABLE | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | HIGH
Estévez-González, 1998^2^ | SOME CONCERNS | NOT APPLICABLE | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Hendrie, 2011^3^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | NOT APPLICABLE | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Villalpando, 2015^5^ | LOW | LOW | NOT APPLICABLE | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

Table 32 Risk of bias for observational studies comparing dairy and dairy products with different amounts of total fat and risk of cardiovascular disease in children^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
McGovern, 2022^4^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi:10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 33 Evidence examining the relationship between low-fat dairy, compared to high-fat dairy, consumption and risk of cardiovascular disease in adults^a^

Study and Participant Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Methodological Considerations
Jamrozik, 2000^40^; PCS, Australia, Perth Community Stroke Study; Analytic N = 787; Participant characteristics:; - Age: 75 y (median); ≥18 y at baseline; - Female: NR; - Race and/or ethnicity: NR; - SEP: NR; - BMI: NR; - Health Status: Participants without stroke; 15% with history of MI or stroke; Participants were matched for sex and 5-y birth cohort of age of the original case-control study; 18+ y at baseline | Exposure and Comparators:; - Reduced fat or skim milk; - Full-fat milk; Exposure assessment method: Interview at baseline; Baseline intake of study foods: 73% eat meat >4 times per week (baseline intake on milk NR); Outcome(s): Major vascular event: Death from coronary disease, stroke, ruptured aortic aneurysm, peripheral vascular disease or mesenteric thrombosis, or nonfatal MI, or nonfatal stroke; Outcome assessment methods and timing: Hospital morbidity data system, Mortality records. Followed-up by certifying or attending physician at 4 y follow-up | [underlined: Major vascular event, HR (95% CI)]; Full-fat: REF; Reduced fat or skim milk: 0.63 (0.40, 0.98) | Key confounders accounted for: Sex, age; Key confounders NOT accounted for: Race and/or ethnicity, socioeconomic position, physical activity, anthropometry, smoking, alcohol, diet quality, total energy intake; Other covariates accounted for: None; Limitations: Many of the covariates were not accounted for. Exposure data not fully defined. Possibly single time point measure. Timing of exposure is unclear.; Funding: Healthway, the Western Australian Health Promotion Foundation
Laursen, 2018^43^; PCS, Denmark, Danish Diet, Cancer, and Health; Analytic N = 55,211; Participant characteristics:; - Age: 56 y; 51-63 y; - Female: 52%; - Race and/or ethnicity: NR; - SEP: 24% with elementary and secondary education ≥10 y; - BMI 25.5 kg/m2; - Health Status: 16% HTN; 7% Hypercholesterolemia; Excluded those <50 y and >64 y not born in Denmark, existing cancer diagnosis at baseline, stroke before baseline, missing data | Exposure and Comparators: Continuous (1 svg/d substitution); - Low-fat milk for: whole-fat milk, buttermilk Whole milk for buttermilk; - Semi-skimmed fermented milk for: whole-fat fermented milk, low-fat milk, whole-fat milk, buttermilk; - Whole-fat fermented milk for: low-fat milk, whole-fat milk, buttermilk; - Cheese for: low-fat milk, whole-fat milk, buttermilk, semi-skimmed fermented milk, whole-fat fermented milk, butter; Substitution of dairy foods:; - Low-fat milk (skimmed milk, 0.3% fat; semi-skimmed milk, 1.5% fat); 1 svg = 200 g; - Whole-fat milk (3.5% fat); 1 svg = 200 g; - Buttermilk (0.5% fat); 1 svg = 200 g; - Semi-skimmed fermented milk (yogurt-type products with 1.5% fat, with or without added fruit); 1 svg = 200 g; - Whole-fat fermented milk (yogurt-type products with 3.5% fat, with or without added fruit); 1 svg = 200 g; - Cheese (semi-hard cheese, soft matured cheese, blue cheese, cottage cheese and cream cheese); 1 svg = 20 g; - Butter (details NR); 1 svg = 6 g; Exposure assessment method: FFQ at baseline; Baseline intake of study foods: Median (80% central range) in svg/d; - Low-fat milk: 0.21 (0.03-2.56); - Whole-fat milk: 0.05 (0.01-0.52); - Buttermilk: 0.03 (0.00-0.44); - Semi-skimmed fermented milk: 0.02 (0.00-0.80); - Whole-fat fermented milk: 0.06 (0.01-1.00); - Cheese: 1.43 (0.50-3.44); - Butter: 1.55 (0.00-5.07); - Fresh red meat: 0.52 (0.27-0.94); - Processed red meat: 1.64 (0.53-3.96); Outcome(s): Stroke (total, ischemic, intracerebral hemorrhagic, subarachnoid hemorrhagic, or unspecified type of stroke). Ischemic stroke further classified according to TOAST-criteria as large artery atherosclerosis, lacunar (small-vessel occlusion), cardioembolism, and stroke of other or unknown etiology.; Outcome assessment methods and timing: Danish National Patient Registry at 13.4 y follow-up | [underlined: Total stroke by 1 svg/d substitution, HR (95% CI)]; Low-fat milk for whole-fat milk: 0.97 (0.91, 1.04); Semi-skimmed fermented milk for whole-fat fermented milk: 1.08 (0.91, 1.28); [underlined: Ischemic stroke by 1 svg/d substitution, HR (95% CI)]; Low-fat milk for whole-fat milk: 0.97 (0.90, 1.04); Semi-skimmed fermented milk for whole-fat fermented milk: 1.14 (0.94, 1.38); [underlined: Intracerebral hemorrhagic stroke by 1 svg/d] substitution, HR (95% CI); Low-fat milk for whole-fat milk: 1.06 (0.87, 1.29); Semi-skimmed fermented milk for whole-fat fermented milk: 1.11 (0.68, 1.80); [underlined: Subarachnoid hemorrhagic stroke by 1 svg/d] substitution, HR (95% CI); Low-fat milk for whole-fat milk: 0.85 (0.67, 1.09); Semi-skimmed fermented milk for whole-fat fermented milk: 0.66 (0.34, 1.29); Data also provided by ischemic stroke sub-type (large artery atherosclerosis, lacunar, cardioembolism); By 1 svg/d substitution, HR (95% CI); Low-fat milk for buttermilk; Total stroke: 0.97 (0.88, 1.06); Ischemic stroke: 0.97 (0.87, 1.07); Intracerebral hemorrhagic stroke: 0.94 (0.74, 1.20); Subarachnoid hemorrhagic stroke: 1.01 (0.68, 1.51); Whole-fat milk for buttermilk; Total stroke: 1.00 (0.90, 1.11); Ischemic stroke: 1.00 (0.89, 1.12); Intracerebral hemorrhagic stroke: 0.89 (0.66, 1.20); Subarachnoid hemorrhagic stroke: 1.19 (0.77, 1.83); Semi-skimmed fermented milk for low-fat milk; Total stroke: 0.99 (0.87, 1.13); Ischemic stroke: 1.00 (0.87, 1.15); Intracerebral hemorrhagic stroke: 0.97 (0.67, 1.39); Subarachnoid hemorrhagic stroke: 1.00 (0.57, 1.74); Semi-skimmed fermented milk for whole-fat milk; Total stroke: 0.96 (0.84, 1.10); Ischemic stroke: 0.97 (0.83, 1.12); Intracerebral hemorrhagic stroke: 1.02 (0.69, 1.51); Subarachnoid hemorrhagic stroke: 0.85 (0.48, 1.49); Semi-skimmed fermented milk for buttermilk; Total stroke: 0.96 (0.82, 1.12); Ischemic stroke: 0.97 (0.82, 1.15); Intracerebral hemorrhagic stroke: 0.91 (0.59, 1.39); Subarachnoid hemorrhagic stroke: 1.01 (0.52, 1.97); Whole-fat fermented milk for low-fat milk; Total stroke: 0.91 (0.80, 1.04); Ischemic stroke: 0.88 (0.76, 1.01); Intracerebral hemorrhagic stroke: 0.87 (0.60, 1.26); Subarachnoid hemorrhagic stroke: 1.51 (0.97, 2.37); Whole-fat fermented milk for whole-fat milk; Total stroke: 0.89 (0.77, 1.02); Ischemic stroke: 0.85 (0.73, 0.99); Intracerebral hemorrhagic stroke: 0.92 (0.61, 1.39); Subarachnoid hemorrhagic stroke: 1.29 (0.80, 2.09); Whole-fat fermented milk for buttermilk; Total stroke: 0.89 (0.76, 1.04); Ischemic stroke: 0.85 (0.71, 1.01); Intracerebral hemorrhagic stroke: 0.82 (0.53, 1.27); Subarachnoid hemorrhagic stroke: 1.53 (0.85, 2.77); Cheese for low-fat milk; Total stroke: 0.96 (0.92, 1.01); Ischemic stroke: 0.97 (0.92, 1.02); Intracerebral hemorrhagic stroke: 0.91 (0.80, 1.03); Subarachnoid hemorrhagic stroke: 1.02 (0.84, 1.25); Cheese for whole-fat milk; Total stroke: 0.93 (0.87, 1.00); Ischemic stroke: 0.94 (0.87, 1.01); Intracerebral hemorrhagic stroke: 0.96 (0.78, 1.18); Subarachnoid hemorrhagic stroke: 0.87 (0.68, 1.12); Cheese for buttermilk; Total stroke: 0.93 (0.85, 1.02); Ischemic stroke: 0.94 (0.84, 1.04); Intracerebral hemorrhagic stroke: 0.85 (0.66, 1.10); Subarachnoid hemorrhagic stroke: 1.03 (0.69, 1.55); [underlined: Cheese for semi-skimmed fermented milk]; Total stroke: 0.97 (0.85, 1.10); Ischemic stroke: 0.97 (0.84, 1.12); Intracerebral hemorrhagic stroke: 0.94 (0.65, 1.35); Subarachnoid hemorrhagic stroke: 1.02 (0.59, 1.78); Cheese for whole-fat fermented milk; Total stroke: 1.05 (0.92, 1.20); Ischemic stroke: 1.11 (0.96, 1.28); Intracerebral hemorrhagic stroke: 1.04 (0.72, 1.50); Subarachnoid hemorrhagic stroke: 0.67 (0.43, 1.06); Cheese for butter; Total stroke: 0.96 (0.92, 1.00); Ischemic stroke: 0.96 (0.92, 1.00); Intracerebral hemorrhagic stroke: 0.98 (0.87, 1.10); Subarachnoid hemorrhagic stroke: 0.97 (0.82, 1.16); Data also provided by ischemic stroke sub-type (large artery atherosclerosis, lacunar, cardioembolism) | Key confounders accounted for: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol intake, diet quality (intake of fruit, vegetables, red meat, processed meat, and fish), total energy intake; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: HTN, hypercholesterolemia, diabetes, and previous myocardial infarction; Limitations: Exposure measured at baseline only; No preregistered data analysis plan; Funding: Danish Council for Strategic Research (Innovation Fund Denmark)
Raziani, 2017^31^; RCT-parallel, Denmark; Analytic N = 164 (Regular-fat cheese: n=50, Reduced-fat cheese: n=51, Carbohydrate: n=49); Adequately powered: Yes; Study aims: To compare the effects of regular-fat cheese with an equal amount of reduced-fat cheese and an isocaloric amount of carbohydrate-rich foods on LDL cholesterol and risk factors for the metabolic syndrome.; Participant characteristics:; - Age: ~54 y; - Female: 66%; - Race and/or ethnicity: NR; - SEP: NR; - BMI ~29 (3); - Health Status: 100% with ≥2 MetS risk factors; Excluded chronic diseases (known T2D, CVD, or other chronic diseases that could affect the study outcome), milk allergy, use of prescription medicine that could affect results of the study (e.g., lipid-lowering agents), >10hr of strenuous physical activity/wk, drug and alcohol abuse, blood donation <1mo before study commencement or during the study period, simultaneous participation in other clinical studies, pregnant or lactating woman or women who were planning to become pregnant during the intervention, inability to comply with the procedures required by the protocol. | Intervention and Comparators:; - Reduced-fat cheese: 40g of reduced-fat Danbo (13% fat) and 40g sharp cheddar (16% fat) cheese providing 15g Fat and 8.9g SFA; - Carbohydrate control: 90g white-wheat bread and 25g sugar-sweetened jam providing 1.9g Fat and 0.2g SFA; Compared to the regular-fat cheese, the carbohydrate control contained the same amount of energy and the reduced-fat cheese contained ~17% less energy.; During a 2wk run-in, all participants received 250 mL/d of skimmed milk and were asked to refrain from consuming other dairy products.; Regular-fat cheese: 40g of regular-fat Danbo (25% fat) and 40g of sharp cheddar (32% fat) cheese providing 23.4g Fat and 14.4g SFA; Intervention duration: 12 wk; Other Group Differences: All participants were provided with 250mL of skimmed milk (0.1% fat) per day throughout intervention and asked not to consume any other dairy products. Remaining part of participant’s habitual diet was not controlled and they were asked to maintain their usual diets. NS difference in fiber intake from 3d weighed dietary records at 12wk. Energy not matched but no significant differences found between groups.; Compliance: Yes, >95% in all groups and NS differences between groups in % of test food consumed compared with test food handed to participants; Baseline intake of study foods: All drank 250 mL/d of skimmed milk (2wk run-in); Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood collection and blood pressure (3 consecutive measurements, mean of last 2 was recorded) at baseline, 6wk, and 12wk | [underlined: LDL (mmol/L)]; Within group: Mean (SD) at baseline, Mean (SEM) at 12wk; Reduced-fat cheese: 3.36 (0.88), 3.45 (0.13); Regular-fat cheese: 3.34 (0.81), 3.51 (0.11); Between group: change over 12wk, Mean (SEM); Reduced-fat cheese: 0.09 (0.08); Regular-fat cheese: 0.17 (0.07) P=0.42; [underlined: HDL (mmol/L)]; Within group: Mean (SD) at baseline, Mean (SEM) at 12wk; Reduced-fat cheese: 1.42 (0.33), 1.46 (0.04); Regular-fat cheese: 1.39 (0.37), 1.45 (0.06); Between group: change over 12wk, Mean (SEM); Reduced-fat cheese: 0.05 (0.02); Regular-fat cheese: 0.06 (0.02) P=0.86; [underlined: TG (mmol/L)]; Within group: Mean (SD) at baseline, Mean (SEM) at 12wk; Reduced-fat cheese: 1.26 (0.53), 1.23 (0.07); Regular-fat cheese: 1.31 (0.59), 1.42 (0.11); Between group: change over 12wk, Mean (SEM); Reduced-fat cheese: −0.03 (0.07); Regular-fat cheese: 0.11 (0.09) P=0.11; [underlined: SBP (mmHg)]; Within group: Mean (SD) at baseline, Mean (SEM) at 12wk; Reduced-fat cheese: 128.5 (15.2), 125.2 (2.2); Regular-fat cheese: 131.7 (15.1), 130.5 (1.9); Between group: change over 12wk, Mean (SEM); Reduced-fat cheese: −3.2 (1.3); Regular-fat cheese: −1.1 (1.4) P=0.17; [underlined: DBP (mmHg)]; Within group: Mean (SD) at baseline, Mean (SEM) at 12wk; Reduced-fat cheese: 83.1 (9.5), 81.1 (1.3); Regular-fat cheese: 84.7 (9.1), 83.3 (1.1); Between group: change over 12wk, Mean (SEM); Reduced-fat cheese: −2.0 (0.7); Regular-fat cheese: −1.4 (0.7); P=0.50; [underlined: LDL (mmol/L), Change over 12wk, Mean (SEM)]; Carbohydrate control: 0.03 (0.06); Regular-fat cheese: 0.17 (0.07); P=0.17; [underlined: HDL (mmol/L), Change over 12wk, Mean (SEM)]; Carbohydrate control: 0.01 (0.03); Regular-fat cheese: 0.06 (0.02); P=0.07; [underlined: TG (mmol/L), Change over 12wk, Mean (SEM)]; Carbohydrate control: 0.11 (0.06); Regular-fat cheese: 0.11 (0.09); P=0.88; [underlined: SBP (mmHg), change over 12wk, Mean (SEM)]; Carbohydrate control: −2.0 (1.5); Regular-fat cheese: −1.1 (1.4); P=0.21; [underlined: DBP (mmHg), change over 12wk, Mean (SEM)]; Carbohydrate control: −1.9 (0.7); Regular-fat cheese: −1.4 (0.7); P=0.77 | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Participants were not blinded; Funding: Danish Dairy Research Foundation; Danish Agriculture and Food Council; National Dairy Council (United States); Dairy Farmers of Canada; Centre National Interprofessionel de l’Economie Laitie`re; Dairy Australia; Nederlandse Zuivel Organisatie
Nilsen, 2015^28^; RCT-parallel, Norway; Analytic N = 153 (Norvegia, N=50; Gamalost, N=53; Control, N=50); Adequately powered: NR; Study aims: To assess whether intake of two types of Norwegian cheese, with widely varying fat and calcium content, might influence factors of the metabolic syndrome and serum cholesterol levels differently.; Participant characteristics:; - Age: 43 (16) y; 18-70 y; - Female: 52%; - Race and/or ethnicity: NR; - SEP: 16.6 (2.9)y of education; - BMI 25.7 (3.7); - Health Status: 28% SBP>130 mm Hg; 30% MetS; Excluded <18y, pregnancy, use of BP-lowering medications | Intervention and Comparators:; - Norvegia (high-fat cheese): Gouda-type cheese containing 27 g fat, 17g SFA, and 27g PRO per 100g; serving size = 80 g/day; - Gamalost (low-fat cheese): traditional Norwegian skimmed milk cheese naturally fat-free and containing 0g SFA and 50g PRO per 100g; serving size = 50 g/day; - Control (low cheese intake): asked to limit intake of Norvegia and Gamalost and given a list of cheese to consume (mostly fresh cheese, blue cheese, cream cheese); Intervention duration: 8 wk; Other Group Differences: No change in food intake except increased total dairy and cheese intake in the Gamalost and Norvegia groups; Compliance: Yes, compliance by evaluation of charts of weighed daily cheese intake in a subset of study population.; Baseline intake of study foods: 18.4 (11.9) svg/wk of total dairy; 7.5 (4.6) svg/wk of total cheese; Outcome(s): HDL, SBP, DBP; Outcome assessment methods and timing: Fasting blood collection and 3 consecutive BP measurements (average of 2nd and 3rd measurement was recorded) at baseline and 8wk | [underlined: HDL (mmol/L), Mean Difference (95% CI)]; Within group: change over 8wk; Control (low cheese intake): −0.04 (−0.10, 0.01), P=0.100; Gamalost (low-fat cheese): −0.06 (−0.10, −0.01), P=0.010; Norvegia (high-fat cheese): −0.04 (−0.10, 0.03), P=0.299; Between group: Cheese groups vs Control: Data NR, P=NS; [underlined: SBP (mmHg), Mean Difference (95% CI)]; Within group: change over 8wk; Control (low cheese intake): −5.4 (−8.5, −2.2), P=0.001; Norvegia (high-fat cheese): −3.5 (−5.8, −1.3), P=0.003; Gamalost (low-fat cheese): −4.4 (−7.0, −1.8), P=0.001; Between group: Cheese groups vs Control: Data NR, P=NS; [underlined: DBP (mmHg), Mean Difference (95% CI)]; Within group: change over 8wk; Control (low cheese intake): −1.1 (−3.3, 1.1), P=0.333; Norvegia (high-fat cheese): −0.9 (−2.6, 0.9), P=0.319; Gamalost (low-fat cheese): −2.9 (−4.4, −1.4), P<0.001; Between group: Cheese groups vs Control: Data NR, P=NS | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Participants were not blinded; No power calculation; Funding: Norwegian Research Council; Norwegian Foundation for Research Levy on Agricultural Products; Norwegian Agricultural Agreement Research Fund; TINE SA (Oslo, Norway)
Haring, 2014^38^; PCS, United States, ARIC; Analytic N = 12,066; Participant characteristics:; - Age: ~53.8 (5.7)y; 45-64y; - Female: 56%; - Race and/or ethnicity: 77% White; 23% Black; - SEP: 79% High school graduates; - BMI 27.1 kg/m2; - Health Status: 29% HTN; Excluded participants with self-reported diabetes, fasting blood glucose ≥126 mg/dL, non-fasting blood glucose ≥200 mg/dL or use of diabetes medication, a history of myocardial infarction, stroke, heart failure, coronary bypass surgery, angioplasty or with missing data on covariates of interest.; Participants that reported implausible energy intake or incomplete dietary information were excluded Current smoker: ~26% | Exposure and Comparators: Continuous (1 svg/d substitution); - High-fat dairy; - Low-fat dairy; - Fish/seafood; - Eggs; - Nuts; - Legumes; Exposure assessment method: FFQ at baseline and ~6y follow-up (cumulative average); Baseline intake of study foods: Median: 0.4 svg/d of high-fat dairy, 0.4 svg/d of low-fat dairy, 0.4 svg/d of processed meat, 0.5 svg/d of red meat, 0.3 svg/d of poultry; Outcome(s): CHD (definite or probable MI, or CHD death); Outcome assessment methods and timing: Adjudicated using information from study visits, yearly telephone follow-up calls, review of hospital discharge lists and medical charts, death certificates, next-of-kin interviews, and physician-completed questionnaires at 22 y follow-up | [underlined: CHD per 1 svg/d substitution, HR (95% CI)]; Low-fat dairy for high-fat dairy: 0.93 (0.84, 1.02); [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy; Fish/seafood for high-fat dairy: 0.94 (0.75, 1.19); Low-fat dairy; Fish/seafood for low-fat dairy: 1.02 (0.80, 1.28); [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy; Eggs for high-fat dairy: 0.89 (0.75, 1.06); Nuts for high-fat dairy: 0.90 (0.78, 1.03); Legumes for high-fat dairy: 0.93 (0.73, 1.19); Low-fat dairy; Eggs for low-fat dairy: 0.96 (0.81, 1.14); Nuts for low-fat dairy: 0.97 (0.84, 1.11); Legumes for low-fat dairy: 1.01 (0.79, 1.28); [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy for processed meat: 1.04 (0.90, 1.20); High-fat dairy for red meat: 0.91 (0.74, 1.12); High-fat dairy for poultry: 1.12 (0.90, 1.40); Low-fat dairy for processed meat: 0.96 (0.84, 1.11); Low-fat dairy for red meat: 0.84 (0.68, 1.05); Low-fat dairy for poultry: 1.04 (0.83, 1.30) | Key confounders accounted for: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (all the food items in the table, fiber intake), total energy intake; Key confounders NOT accounted for: None; Other covariates accounted for: Study center, systolic blood pressure, use of antihypertensive and/or lipid lowering medication, HDL, total cholesterol, carbohydrate intake, magnesium intake; Limitations: Only Black and White participants are included, so the findings are not entirely generalizable. No preregistered data analysis plan; Funding: NHLBI/NIH; German Research Foundation; University of Wurzburg
Hu, 1999^52^; PCS, United States, Nurses’ Health Study; Analytic N = 80,082; Participant characteristics:; - Age: ~45.9 (7.1)y; 34-59y; - Female: 100%; - Race and/or ethnicity: NR (but predominantly White, based on other articles from this cohort); - SEP: 100% Nurses; - BMI: 24.2 kg/m2; - Health status: 14% HTN; Excluded those with excessive missing FFQ data (≥10 items blank) or extreme reported total food or energy intake, previous diagnosis of cancer, angina, MI, stroke or other cardiovascular diseases, high serum cholesterol or diabetes. | Exposure and Comparators: Categorical (quintiles of svg/d); - Ratio of high-fat dairy to low-fat dairy; Low-fat dairy included skim or low-fat milk, yogurt and cottage cheese.; High-fat dairy included whole milk, hard or cream cheese, ice cream and butter.; Exposure assessment method: FFQ at baseline and every 2 y for 7 periods; Outcome(s): CHD, including nonfatal MI or fatal coronary disease; Outcome assessment methods and timing: Records reviewed by study physician. Included both confirmed (medical records) and probable (no medical records, 17%) cases. Death identified from state vital records and National Death Index, family or postal system; 14 y follow-up. | Ratio of high-fat dairy to low-fat dairy products; CHD by quintile of the ratio of high-fat to low-fat dairy products, RR; Q1: Ref; Q2: 0.87; Q3: 0.94; Q4: 1.17; Q5: 1.27; P for trend: 0.0004 | Key confounders accounted for: Sex, age, race and/or ethnicity, socioeconomic position (profession), physical activity, anthropometry, smoking, alcohol, diet quality (all the food items in the table), total energy intake; Key confounders NOT accounted for: None; Other covariates accounted for: Time period, menopausal status, parental history of MI before 60 y, vitamin E supplement use, history of hypertension, aspirin use.; Limitations: Participants were predominantly White, with possibly high SEP, so findings are not entirely generalizable. No preregistered data analysis plan; Funding: NIH
Louie, 2013^47^; PCS, Australia, BMES (Blue Mountain Eye Study); Analytic N = 2,625; Participant characteristics:; - Age: 65.4 (9.3)y; 49-97y; - Female: ~56%; - Race and/or ethnicity: NR; - SEP: 60% with degree or above; - BMI 26 (4) kg/m2; - Health Status: 45% HTN; 8% T2D; Excluded those with excessive missing FFQ data, extreme nutrient values or extreme reported energy intake, unidentifiable causes of death or missing baseline data on BMI, smoking status, history of stroke, MI, or T2D; and those with zero whole fat diary intake for exposure of ratio of low fat to whole fat | Exposure and Comparators: Categorical (tertiles of svg/d); - Ratio of low-fat dairy to whole-fat dairy; - Low-fat dairy included low/reduced fat dairy such as reduced fat/skim milk, reduced fat dairy dessert, and low fat cheese; - Whole-fat dairy included whole fat milk, whole fat cheese, and medium fat dairy dessert; Servings sizes used were 250mL for milk, 200g for yogurt, 250mL for custards, and 40g for cheese; Exposure assessment method: FFQ at baseline; Baseline intake of study foods: 1.4% non-consumers of full-fat dairy; 27.6% non-consumers of low/reduced-fat dairy; Outcome(s): CVD mortality (total CVD, stroke, and CHD); Outcome assessment methods and timing: National Death Index at 15 y follow-up | By ratio of low-fat dairy to whole-fat dairy (tertiles of svg/d); [underlined: CVD mortality, HR (95% CI)]; Tertile 1: REF; Tertile 2: 0.88 (0.63, 1.24); Tertile 3: 0.94 (0.68, 1.31); P-trend=0.396; [underlined: Stroke mortality, HR (95% CI)]; Tertile 1: REF; Tertile 2: 1.08 (0.60, 1.96); Tertile 3: 0.81 (0.44, 1.49); P-trend=0.255; [underlined: CHD mortality, HR (95% CI)]; Tertile 1: REF; Tertile 2: 0.83 (0.57, 1.22); Tertile 3: 1.04 (0.72, 1.49); P-trend=0.993 | Key confounders accounted for: Sex, age, socioeconomic position (SES), physical activity, anthropometry, smoking, diet quality (intake of fish, fruit, and vegetables), total energy intake; Key confounders NOT accounted for: Race and/or ethnicity, alcohol; Other covariates accounted for: previous acute myocardial infarction or stroke, stage II hypertension, type 2 diabetes, use of antihypertensive medication, use of statins, change in dairy intake; Limitations: Exposure measured at baseline only; No preregistered data analysis plan; Funding: Dairy Australia
Patterson, 2013^49^; PCS, Sweden, Swedish Mammography Cohort; Analytic N = 33,636; Participant characteristics:; - Age: ~61 y; 39-73y; - Female: 100%; - Race and/or ethnicity: NR; - SEP: 20% postsecondary-level education; - BMI ~25; - Health Status: Generally healthy, without CVD, diabetes, or cancer; 19% HTN; 7% high cholesterol; Excluded those with CVD, cancer, or diabetes; those with usually high or low energy intake (>3 SDs from the log-transformed mean intake) | Exposure and Comparators:; - Substitution of low-fat milk for high-fat milk,; - Substitution of low-fat cultured milk/yogurt for high-fat cultured milk/yogurt; - Substitution of low-fat cheese for high-fat cheese; Low-fat milk: sum of skimmed (0.5% fat) plus semi-skimmed milk (≤1.5% fat); Low-fat cheese: low-fat varieties (10-17%), excluding very-low-fat cheese (e.g., cottage cheese, quark, ~4% fat); Low-fat cultured milk/yogurt: ≤1.5% fat; Categorical (<20, 20–39, 40–59, 60–79, 80–100% low-fat); High-fat milk: full-fat milk (≥3.0% fat); High-fat cheese: full-fat cheese (>17% fat); High-fat cultured milk/yogurt: ≥3.0% fat; Exposure assessment method: FFQ at baseline; Baseline intake of study foods: svg/d: 1.2 (1.3) milk; 0.9 (1.0) cultured milk/yogurt; 2.7 (2.1) cheese; Outcome(s): MI (fatal and nonfatal); Outcome assessment methods and timing: Cause of Death Registry and National Hospital Discharge Registry at 11.6 y follow-up | [underlined: Myocardial infarction, HR (95% CI)]; Substituting low-fat for high-fat dairy, all % modeled as continuous and categorical variable; Milk, low-fat for high-fat Data NR, P=NS; Cultured milk/yogurt, low-fat for high-fat cultured milk/yogurt; Data NR, P=NS; Cheese, low-fat for high-fat cheese Data NR, P=NS | Key confounders accounted for: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol intake, diet quality (consumption of fruit, vegetables, and whole grain foods), total energy intake; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: HTN, high cholesterol, family history of myocardial infarction, aspirin usage, hormone therapy usage; Limitations: Exposure measured at baseline only; No preregistered data analysis plan; Funding: Swedish Council for Working Life and Social Research; Swedish Research Council/Infrastructure Medicine
Dalmeijer, 2013^35^; PCS, The Netherlands, EPIC-NL; Analytic N = 33,625; Participant characteristics:; - Age: 49 (12) y; 49-70 y; - Female: 74%; - Race and/or ethnicity: NR; - SEP: 21% high education; - BMI 25.6 (4.0) kg/m2; - Health Status: 36% HTN; Excluded those with missing data, implausible energy intake (<800 or 4200 kcal/d for men, <500 or >3500 kcal/d for women), CVD, cancer, diabetes; Current smoker: 30% | Exposure and Comparators: Continuous (g/d); Ratio of high-fat dairy to low-fat dairy; Definitions:; - High-fat dairy: milk and milk products with a fat content ≥2g per 100g (whole milk products); cheese products with a fat content ≥20g per 100g; - Low-fat dairy: milk and milk products with a fat content <2g per 100g (skimmed or semi-skimmed milk products); cheese products with a fat content <20g per 100g; - Milk and milk products included all kinds of milk, yogurt, coffee creamers, curd, pudding, porridge, custard, and whipping cream.; - Cheese included all types of cheese except for curd.; Exposure assessment method: FFQ at baseline; Baseline intake of study foods: Median (IQR): 46 (30-67) g/d of high-fat dairy; 230 (106-385) g/d of low-fat dairy; Outcome(s): CHD (fatal or nonfatal) and stroke; Outcome assessment methods and timing: Standardized register for hospital discharge diagnoses, verified against hospital records in a subsample at 13 y follow-up | [underlined: CHD, HR (95% CI)]; Ratio of high-fat dairy to low-fat dairy (g/d): 1.02 (0.98, 1.06); [underlined: Stroke, HR (95% CI)]; Ratio of high-fat dairy to low-fat dairy (g/d): 0.98 (0.93, 1.04) | Key confounders accounted for: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol intake, diet quality (intake of fruit, vegetables, fish, meat, bread, and coffee), total energy intake; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: None; Limitations: Exposure measured at baseline only; No preregistered data analysis plan; Funding: European Commission; Dutch Ministry of Public Health, Welfare and Sports; Netherlands Cancer Registry; LK Research Funds; Dutch Prevention Funds; Zorg Onderzoek Nederland; World Cancer Research Fund; Netherlands Heart Foundation
Holmberg, 2009^39^; PCS, Sweden; Analytic N = 1752; Participant characteristics:; - Age: 50.2 y (6.0), Range: 39-62 y; - Female: 0%; - Race and/or ethnicity: NR; - SEP: 57% farmer; 43% non-farmer; - BMI 26.4 (3.2) kg/m2, Range: 18.3-44.4; - Health Status: Generally healthy; LDL: 3.8 (1.0) mmol/L, Range: 0.5-7.6; SBP: 134 (17), Range: 96-219; Included farmers (≥25hr/wk farming) and age-, sex-, and residential area-matched non-farmers; excluded previous hospitalization for CHD | Exposure and Comparators:; Low-fat dairy: low-fat milk, no butter, seldom/never cream; Low-fat milk;; MUFA/PUFA: low-fat margarine or no fat (spread on sandwiches); All categorical (Yes/No if primary fat level of dairy consumed); High-fat dairy: full-fat milk and/or butter and/or cream, categorical (Yes/No if primary fat level of dairy consumed);; Dairy: High-fat milk;; Dairy: Butter (specifically as spread on sandwiches); Exposure assessment method: FFQ at baseline; Baseline intake of study foods: NR; Outcome(s): Death or hospitalization due to CHD; Outcome assessment methods and timing: National Cause of Death Register (CHD mortality) and Hospital Patient Register (CHD morbidity); assessed across 12 y at 12 y follow-up | [underlined: CVD morbidity over 12 y, by baseline intake, OR (95% CI)]; High-fat dairy (n=1373) = REF; Low-fat dairy (n=346): 1.80 (1.22, 2.66); [underlined: CVD morbidity over 12 y, by baseline intake, OR (95% CI)]; High-fat milk (n=838) = REF; Low-fat milk (n=908): 1.43 (1.00, 2.04); [underlined: CVD morbidity over 12y, by baseline intake, OR (95% CI)]; Butter (n=845) = REF; Low-fat margarine or no fat (n=894): 1.10 (0.78, 1.56) | Key confounders accounted for: Sex (♀ only); Key confounders NOT accounted for: Age, race and/or ethnicity, socioeconomic position, physical activity, anthropometry, smoking, alcohol, diet quality, total energy intake; Other covariates accounted for: LDL, SBP; Limitations: Exposure measured at baseline only; no preregistered data analysis plan; Funding: AFA Insurance, LRF Research Foundation, The Swedish Council for Working Life and Social Research, Kronoberg County Council
Alonso, 2009^25^; RCT-crossover, United States; Analytic N = 45 (Whole-fat: N=23, Low-fat: N=22); Adequately powered: Yes; Study aims: To assess whether supplementing diets with low- or whole-fat dairy products would differentially affect blood pressure levels and weight; Participant characteristics:; - Age: 19 (1.5) y; 18-24 y; - Female: 49%; - Race and/or ethnicity: NR; - SEP: Medium; - BMI 23.5 (3.6) kg/m2; - Health Status: All normotensive; Excluded <18y or >24y, BMI >30 kg/m2, HTN, previous history of CVD, severe gastrointestinal, disease, diabetes, lactose intolerance | Intervention and Comparators:; - Low-fat dairy: 3.5 svg/d (3 servings of milk, half serving of yogurt) supplying 324kcal and 2g saturated fat; 1 svg = 250 g; - Whole-fat dairy: 3.5 svg/d (3 servings of milk and half serving of yogurt) supplying 520kcal and 19g saturated fat; 1 svg = 250; Intervention duration: 8 wk (4wk washout); Other Group Differences: Participants were advised to consume the supplied food during the day and to avoid intake of dairy products from other sources, but not to change their usual diet or lifestyle in other ways. There were no efforts to maintain constant total energy intake.; Compliance: Yes, >95% of intervention days (based on daily dietary records); Baseline intake of study foods: 491.6 (198.0) g/d of total dairy; 117.1 (156.2) g/d of low-fat dairy; Outcome(s): SBP, DBP; Outcome assessment methods and timing: Six BP measurements were taken (3 in left arm and 3 in right arm) with participant in seated position; average of last 5 measurements was used to calculate BP for visits at baseline and after each intervention period | [underlined: SBP (mmHg), Mean (95% CI)]; Within group: change after 8wk; Low-fat dairy: 1.5 (−0.6, 3.6), P=0.15; Whole-fat dairy: 2.1 (0.1, 4.0), P=0.04; Between group: change after 8wk; −0.6 (−3.3, 2.1), P=0.68; [underlined: DBP (mmHg), Mean (95% CI)]; Within group: change after 8wk; Low-fat dairy: 0.6 (−1.0, 2.2), P=0.46; Whole-fat dairy: 0.8 (−0.9, 2.6), P=0.34; Between group: change after 8wk; −0.2 (−2.5, 2.0), P=0.82 | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: No information on randomization or allocation procedures.; Energy intake significantly higher during whole-fat dairy period. Change in body weight also significant.; Funding: Spanish Ministry of Health, Instituto de Salud Carlos III; Central Lechera Asturiana
Wang, 2021^50^; PCS, United States, NHANES; Analytic N = 29,283; Participant characteristics:; - Age: 46.7 (0.22)y; - Female: 51%; - Race and/or ethnicity: Non-Hispanic; White: ~ 69%; Non-Hispanic Black: ~ 11%; Hispanic-Mexican: ~9%; Other: ~11%; - SEP: Less than high school: ~10%; High school graduate: ~25%; More than high school: ~65%; - BMI ~28 kg/m2; - Health Status: Generally healthy; Excluded those with varying frequency of milk consumption or less than once a week, without data on milk types and loss of follow-up for mortality status, who died within 12-month or had a follow-up period less than 12 months; and energy consumption less than 500 or beyond 5000 kcal/day | Exposure and Comparators:; - Whole-fat milk (3-4g/100g fat); - 2% Low-fat milk (2g/100g); - ≤1% Low-fat milk (1g/100g low-fat, 0.5g/100g low-fat, skim and nonfat milk); Exposure assessment method: 24-h dietary recall; Baseline intake of study foods: 33% drink regular milk, 38% drink 2g/100g of low-fat milk, 25% drink ≤1g/100g of low-fat milk, and 4% drink other milk; Outcome(s): Heart disease mortality; stroke mortality; Outcome assessment methods and timing: National Death Index at 8.3 y follow-up | [underlined: Heart disease mortality, HR (95% CI)]; Whole-fat milk: REF; 2% Milk: 0.73 (0.55, 0.97), P=0.029; ≤1% Milk: 0.67 (0.49, 0.91), P=0.012; P-trend: 0.009; [underlined: Stroke mortality, HR (95% CI)]; Whole-fat milk: REF; 2% Milk: 0.87 (0.46, 1.66), P=0.654; ≤1% Milk: 0.65 (0.35, 1.19), P=0.181; P-trend: NR; [underlined: CVD mortality, HR (95% CI)]; Whole-fat milk: REF; 2% Milk: 0.71 (0.51, 0.98); ≤1% Milk: 0.69 (0.48, 0.97); P-trend: 0.023 | Key confounders accounted for: Sex, age, race and/or ethnicity, socioeconomic position (education, marital status, poverty to income ratio), physical activity, anthropometry (BMI), smoking, alcohol, diet quality (protein, SFAs, MUFAs, PUFAs, intakes of fruits or vegetables, and red/processed meat), total energy intake; Key confounders NOT accounted for: N/A; Other covariates accounted for: milk consumption (≥ 1 times/week, or ≥ 1 times/day), HTN, CVD, T2D, COPD, cancer, TG, TC, HDL, eGFR; Limitations: Exposure measured at baseline only; No preregistered data analysis plan; Funding: National Key R&D Program; Major Instrument Development Project of the National Natural Science Foundation of China; National Natural Science Foundation of China; Key Laboratory of Myocardial Ischemia, Ministry of Education of China
Laursen, 2019^44^; PCS, The Netherlands, EPIC-NL (comprised of 2 cohorts: Prospect & MORGEN); Analytic N = 36,886; Participant characteristics:; - Age: 51 y; 31-63 y; - Female: 75%; - Race and/or ethnicity: NR; - SEP: 58% low educational attainment (primary up to intermediate vocational); - BMI 25.1 kg/m2; - Health Status: 37% HTN; 8.5% Hypercholesterolemia; Excluded participants that did not permit register linkage; previous stroke; poor diet reporters (top and bottom 0.5% of the ratio of energy intake to estimated basal metabolic rate); missing data on exposures or covariates | Exposure and Comparators: Continuous (1 svg/d substitution; also conducted sensitivity analyses with isocaloric 100kcal/d substitutions); - Low-fat yogurt for: whole-fat yogurt, low-fat milk, whole-fat milk, buttermilk, cheese, butter; - Whole-fat yogurt for: low-fat milk, whole-fat milk, buttermilk, cheese, butter; - Low-fat milk for: whole-fat milk, buttermilk, cheese, butter; - Whole milk for: buttermilk, cheese, butter; - Buttermilk for: cheese, butter; - Cheese for butter; Substitution of dairy foods:; - Low-fat milk (skimmed and semi-skimmed milk, <2% fat); 1 svg = 200 g; - Whole-fat milk (whole-fat, raw and powdered milk, ≥3% fat); 1 svg = 200 g; - Buttermilk (details NR); 1 svg = 200 g; - Low-fat yogurt products (skimmed and semi-skimmed regular and drink yogurt, <2% fat, curd); 1 svg = 200 g; - Whole-fat yogurt products (regular and drink yogurt, ≥3% fat); 1 svg = 200 g; - Cheese (details NR); 1 svg = 20 g; - Butter (details NR); 1 svg = 6 g; Exposure assessment method: FFQ at baseline; Baseline intake of study foods: Median (80% central range) in svg/d; Low-fat milk: 0.46 (0.05-1.71); Whole-fat milk: 0.15 (0.01-0.59); Buttermilk: 0.00 (0.00-1.00); Low-fat yogurt: 0.15 (0.01-0.68); Whole-fat yogurt: 0.05 (0.00-0.28); Cheese: 1.50 (0.36-3.38); Butter: 0.46 (0.12-2.06); Fresh red meat: 0.41 (0.11-0.70); Processed red meat: 1.37 (0.20-4.07); Outcome(s): Stroke (total, ischaemic, hemorrhagic); Outcome assessment methods and timing: Standardized register for hospital discharge diagnoses; 15y median follow up, participants followed until the date of an incident stroke, death from another cause, loss to follow-up or end of study at Median: 15 y follow-up | Total stroke, by 1 svg/d substitution, HR (95% CI); Low-fat yogurt for whole-fat yogurt: 1.32 (0.73, 2.36); Low-fat milk for whole-fat milk: 0.99 (0.78, 1.25); Ischemic stroke, by 1 svg/d substitution, HR (95% CI); Low-fat yogurt for whole-fat yogurt: 2.27 (0.99, 5.22); Low-fat milk for whole-fat milk: 0.92 (0.68, 1.23); Hemorrhagic stroke, by 1 svg/d substitution, HR (95% CI); Low-fat yogurt for whole-fat yogurt: 0.70 (0.25, 1.93); Low-fat milk for whole-fat milk: 1.38 (0.82, 2.33); Also provided data by 100kcal substitutions between dairy products; [underlined: Total stroke by 1 svg/d substitution, HR (95% CI)]; Low-fat yogurt for low-fat milk: 0.91 (0.75, 1.11); Low-fat yogurt for whole-fat milk: 0.90 (0.70, 1.16); Low-fat yogurt for buttermilk: 0.93 (0.76, 1.14); Low-fat yogurt for cheese: 0.91 (0.76, 1.10); Low-fat yogurt for butter: 0.91 (0.76, 1.10); Whole-fat yogurt for low-fat milk: 0.69 (0.40, 1.20); Whole-fat yogurt for whole-fat milk: 0.68 (0.39, 1.22); Whole-fat yogurt for buttermilk: 0.70 (0.41, 1.22); Whole-fat yogurt for cheese: 0.69 (0.40, 1.19); Whole-fat yogurt for butter: 0.69 (0.40, 1.19); Low-fat milk for buttermilk: 1.02 (0.90, 1.16); Low-fat milk for cheese: 1.00 (0.90, 1.12); Low-fat milk for butter: 1.00 (0.90, 1.11); Whole-fat milk for buttermilk: 1.03 (0.84, 1.26); Whole-fat milk for cheese: 1.01 (0.84, 1.23); Whole-fat milk for butter: 1.01 (0.83, 1.24); Buttermilk for cheese: 0.99 (0.88, 1.10); Buttermilk for butter: 0.98 (0.88, 1.10); Cheese for butter: 1.00 (0.92, 1.08); [underlined: Ischaemic stroke by 1 svg/d substitution, HR (95% CI)]; Low-fat yogurt for low-fat milk: 0.87 (0.67, 1.15); Low-fat yogurt for whole-fat milk: 0.80 (0.58, 1.11); Low-fat yogurt for buttermilk: 0.89 (0.68, 1.18); Low-fat yogurt for cheese: 0.88 (0.69, 1.14); Low-fat yogurt for butter: 0.88 (0.69, 1.13); Whole-fat yogurt for low-fat milk: 0.38 (0.18, 0.85); Whole-fat yogurt for whole-fat milk: 0.35 (0.16, 0.79); Whole-fat yogurt for buttermilk: 0.39 (0.18, 0.87); Whole-fat yogurt for cheese: 0.39 (0.18, 0.85); Whole-fat yogurt for butter: 0.39 (0.18, 0.85); Low-fat milk for buttermilk: 1.02 (0.86, 1.21); Low-fat milk for cheese: 1.01 (0.88, 1.17); Low-fat milk for butter: 1.01 (0.88, 1.16); Whole-fat milk for buttermilk: 1.12 (0.86, 1.44); Whole-fat milk for cheese: 1.11 (0.87, 1.40); Whole-fat milk for butter: 1.10 (0.86, 1.42); Buttermilk for cheese: 0.99 (0.86, 1.15); Buttermilk for butter: 0.99 (0.85, 1.15); Cheese for butter: 1.00 (0.89, 1.11); [underlined: Hemorrhagic stroke by 1 svg/d substitution, HR (95% CI)]; Low-fat yogurt for low-fat milk: 0.90 (0.63, 1.30); Low-fat yogurt for whole-fat milk: 1.25 (0.74, 2.11); Low-fat yogurt for buttermilk: 1.02 (0.70, 1.47); Low-fat yogurt for cheese: 0.95 (0.68, 1.32); Low-fat yogurt for butter: 0.88 (0.64, 1.22); Whole-fat yogurt for low-fat milk: 1.30 (0.50, 3.37); Whole-fat yogurt for whole-fat milk: 1.79 (0.63, 5.08); Whole-fat yogurt for buttermilk: 1.46 (0.56, 3.82); Whole-fat yogurt for cheese: 1.36 (0.53, 3.47); Whole-fat yogurt for butter: 1.27 (0.50, 3.24); Low-fat milk for buttermilk: 1.12 (0.88, 1.44); Low-fat milk for cheese: 1.05 (0.85, 1.28); Low-fat milk for butter: 0.98 (0.81, 1.19); Whole-fat milk for buttermilk: 0.81 (0.51, 1.29); Whole-fat milk for cheese: 0.76 (0.49, 1.17); Whole-fat milk for butter: 0.71 (0.45, 1.11); Buttermilk for cheese: 0.93 (0.76, 1.15); Buttermilk for butter: 0.87 (0.71, 1.07); Cheese for butter: 0.93 (0.81, 1.07); Also provided data by 100kcal substitutions between dairy products | Key confounders accounted for: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol intake, diet quality (Dutch Health Diet Index 2015), total energy intake; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: HTN; hypercholesterolemia; DM; myocardial infarction; cohort; Limitations: Exposure measured at baseline only; No preregistered data analysis plan; Funding: European Commission; Dutch Ministry of Health, Welfare, and Sports; Netherlands Organisation for Health Research and Development; World Cancer Research Fund
Laursen, 2022^45^; PCS, Denmark, Danish Diet, Cancer, and Health; Analytic N = 55775; Participant characteristics:; - Age: 56.2 y; 51-63 y; - Female: 52%; - Race and/or ethnicity: NR; - SEP: 21% educational attainment >10y BMI 25.5 kg/m2; - Health Status: 16% HTN; 7.5% Hypercholesterolemia; Excluded those <50y and >64y not born in Denmark, existing cancer diagnosis at baseline, missing data on any exposure or covariate | Exposure and Comparators: Continuous (1 svg/d substitution); - Low-fat milk (skimmed milk, 0.3% fat; semi-skimmed milk, 1.5% fat); 1 svg = 200 g; - Whole milk (whole-fat milk, 3.5% fat); 1 svg = 200 g; - Buttermilk (0.5% fat); 1 svg = 200 g; - Whole-fat yogurt (whole-fat yogurt products with 3·5% fat, with and without added fruit); 1 svg = 200 g; - Low-fat yogurt (semi-skimmed yogurt products with 1·5% fat, with and without added fruit); 1 svg = 200 g; - Cheese (semi-hard cheese, soft matured cheese, blue cheese, cottage cheese and cream cheese); 1 svg = 20 g; Substitution of dairy foods:; - Low-fat yogurt for: whole-fat yogurt, low-fat milk, whole-fat milk, buttermilk, cheese, butter; - Whole-fat yogurt for: low-fat milk, whole-fat milk, buttermilk, cheese, butter; - Low-fat milk for: whole-fat milk, buttermilk, cheese, butter; - Whole milk for: buttermilk, cheese, butter; - Buttermilk for: cheese, butter; - Cheese for butter; Exposure assessment method: FFQ at baseline; Baseline intake of study foods: Median (80% central range) in g/d; - Low-fat milk: 42 (6-513); - Whole-fat milk: 10 (3-104); - Buttermilk: 6 (0-88); - Low-fat yogurt: 3 (0-160); - Whole-fat yogurt: 13 (1-200); - Cheese: 29 (10-69); - Butter: 9 (0-30); - Red meat: 78 (41-141); - Processed meat: 25 (8-60); Outcome(s): CVD mortality; Outcome assessment methods and timing: Danish Causes of Death register at 19 y follow-up | [underlined: CVD mortality by 1 svg/d substitution, HR (95% CI)]; Men (n=26,614; cases=1491); Low-fat milk for whole-fat milk: 0.97 (0.91, 1.04); Low-fat yogurt for whole-fat yogurt: 1.10 (0.88, 1.38); Women (n=29,161; cases=668); Low-fat milk for whole-fat milk: 0.95 (0.83, 1.08); Low-fat yogurt for whole-fat yogurt: 0.93 (0.71, 1.21); Also conducted sensitivity analyses excluding participants with MI or stroke at baseline, poor energy reporters (top and bottom 0.5% of the ratio of reported energy intake to EER), and non-consumers of any dairy subgroup, as well as analyses restricting to non-smokers; [underlined: CVD mortality by 1 svg/d substitution, HR (95% CI)]; Men (n=26,614; cases=1491); Low-fat milk for buttermilk: 1.11 (0.96, 1.27); Low-fat milk for low-fat yogurt: 0.95 (0.80, 1.12); Low-fat milk for whole-fat yogurt: 1.04 (0.89, 1.22); Low-fat milk for cheese: 1.07 (1.02, 1.13); Whole-fat milk for buttermilk: 1.14 (0.98, 1.32); Whole-fat milk for low-fat yogurt: 0.98 (0.82, 1.15); Whole-fat milk for whole-fat yogurt: 1.07 (0.90, 1.27); Whole-fat milk for cheese: 1.10 (1.02, 1.19); Buttermilk for low-fat yogurt: 0.86 (0.69, 1.06); Buttermilk for whole-fat yogurt: 0.94 (0.76, 1.17); Buttermilk for cheese: 0.97 (0.84, 1.11); Low-fat yogurt for cheese: 1.13 (0.96, 1.33); Whole-fat yogurt for cheese: 1.03 (0.87, 1.21); Women (n=29,161; cases=668); Low-fat milk for buttermilk: 0.96 (0.84, 1.10); Low-fat milk for low-fat yogurt: 1.01 (0.83, 1.23); Low-fat milk for whole-fat yogurt: 0.94 (0.76, 1.16); Low-fat milk for cheese: 1.06 (0.98, 1.15); Whole-fat milk for buttermilk: 1.01 (0.85, 1.20); Whole-fat milk for low-fat yogurt: 1.07 (0.86, 1.32); Whole-fat milk for whole-fat yogurt: 0.99 (0.78, 1.26); Whole-fat milk for cheese: 1.12 (0.98, 1.28); Buttermilk for low-fat yogurt: 1.06 (0.84, 1.33); Buttermilk for whole-fat yogurt: 0.98 (0.77, 1.26); Buttermilk for cheese: 1.11 (0.96, 1.28); Low-fat yogurt for cheese: 1.05 (0.86, 1.27); Whole-fat yogurt for cheese: 1.13 (0.91, 1.39); Also conducted sensitivity analyses excluding participants with MI or stroke at baseline, poor energy reporters (top and bottom 0.5% of the ratio of reported energy intake to EER), and non-consumers of any dairy subgroup, as well as analyses restricting to non-smokers | Key confounders accounted for: Sex, age, socioeconomic position (educational attainment), physical activity, anthropometry, smoking, alcohol intake, diet quality (intake of fruit, vegetables, red meat, processed meat, and fish), total energy intake; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: Date of inclusion (as stratum variable); HTN; hypercholesterolemia; Limitations: Exposure measured at baseline only; No preregistered data analysis plan; Funding: Danish Cancer Society
Kvist, 2020^42^; PCS, Denmark, Danish Diet, Cancer, and Health; Analytic N = 54,903; Participant characteristics:; - Age: 56 y; 50-64 y; - Female: 53%; - Race and/or ethnicity: NR (100% Danish); - SEP: 33% education length <8y; - BMI 25.5 kg/m2; - Health Status: Generally healthy, without history of cancer or MI; Excluded those with Hx cancer; Hx MI; incomplete data on exposure or covariates | Exposure and Comparators: Continuous (1 svg/d substitution); - Whole-fat milk with: low-fat milk, whole-fat yogurt, low-fat yogurt, cheese; - Low-fat milk with: low-fat yogurt, whole-fat yogurt, cheese; - Buttermilk with: low-fat milk, whole-fat milk, low-fat yogurt, whole-fat yogurt, cheese; - Whole-fat yogurt with: low-fat yogurt, cheese; - Low-fat yogurt with cheese; - Butter with cheese; Substitution of dairy foods:; - Whole-fat milk (3.5% fat); 1 svg = 200 g; - Low-fat milk (skimmed milk, 0.3% fat; semi-skimmed milk, 1.5% fat); 1 svg = 200 g; - Buttermilk (0.5% fat); 1 svg = 200 g; - Whole-fat yogurt (3.5% fat); 1 svg = 200 g; - Low-fat yogurt (1.5% fat); 1 svg = 200 g; - Cheese (fat NR; semi-hard cheese, soft matured cheese, blue cheese, cottage cheese and cream cheese); 1 svg = 20 g; - Butter (details NR); 1 svg = 6 g; Exposure assessment method: FFQ at baseline; Baseline intake of study foods: Median (80% central range) in svg/d; cohorts, cases:; Red meat: 0.52 (0.27-0.93), 0.59 (0.31-1.04); Processed meat: 1.64 (0.53-3.96), 2.09 (0.67-4.66); Whole-fat milk: 0.05 (0.02-0.52), 0.05 (0.15-1.02); Low-fat milk: 0.21 (0.03-2.56), 0.22 (0.03-2.58); Buttermilk: 0.03 (0-0.44), 0.03 (0-0.38); Whole-fat yogurt: 0.06 (0.01-1), 0.05 (0.01-0.82); Low-fat yogurt: 0.02 (0-0.8), 0 (0-0.51); Cheese: 1.43 (0.50-3.44), 1.33 (0.45-3.26); Butter: 1.56 (0-5.08), 1.97 (0-5.28); Outcome(s): Myocardial infarction; Outcome assessment methods and timing: Danish National Patient Register and Danish Register of Causes of Death at 15.9 y follow-up | [underlined: Myocardial infarction by 1 svg/d substitution, HR (95% CI)]; Low-fat milk for whole-fat milk: 0.97 (0.92, 1.02); Low-fat yogurt for whole-fat yogurt: 0.99 (0.85, 1.15); Men; Low-fat milk for whole-fat milk: 0.97 (0.92, 1.03); Low-fat yogurt for whole-fat yogurt: 0.97 (0.80, 1.19); Women; Low-fat milk for whole-fat milk: 0.94 (0.84, 1.05); Low-fat yogurt for whole-fat yogurt:1.02 (0.84, 1.26); [underlined: Myocardial Infarction, HR (95% CI), per 1 svg] Replacement of whole-fat milk with:; - whole-fat yogurt: 0.89 (0.79, 1.00); - low-fat yogurt: 0.88 (0.78, 0.99); - cheese: 0.93 (0.88, 0.98); Replacement of low-fat milk with:; - low-fat yogurt: 0.91 (0.81, 1.01); - whole-fat yogurt: 0.92 (0.82, 1.02); - cheese: 0.96 (0.92, 0.99); Replacement of buttermilk with:; - low-fat milk: 1.01 (0.93, 1.10); - whole-fat milk: 1.05 (0.95, 1.14); - low-fat yogurt: 0.92 (0.80, 1.06); - whole-fat yogurt: 0.93 (0.81, 1.07); - cheese: 0.97 (0.89, 1.05); Replacement of whole-fat yogurt with cheese: 1.04 (0.93, 1.17); Replacement of low-fat yogurt with cheese: 1.05 (0.94, 1.19); Replacement of butter with cheese: 0.98 (0.95, 1.02); [underlined: Myocardial Infarction, HR (95% CI), per 1 svg, men only]; Replacement of whole-fat milk with:; - whole-fat yogurt: 0.91 (0.78, 1.04); - low-fat yogurt: 0.89 (0.76, 1.04); - cheese: 0.95 (0.89, 1.01); Replacement of low-fat milk with:; - low-fat yogurt: 0.91 (0.78, 1.06); - whole-fat yogurt: 0.94 (0.82, 1.07); - cheese: 0.98 (0.94, 1.02); Replacement of buttermilk with:; - low-fat milk: 1.03 (0.92, 1.15); - whole-fat milk: 1.06 (0.94, 1.20); - low-fat yogurt: 0.94 (0.78, 1.13); - whole-fat yogurt: 0.96 (0.81, 1.15); - cheese: 1.01 (0.90, 1.13); Replacement of whole-fat yogurt with cheese: 1.05 (0.91, 1.20); Replacement of low-fat yogurt with cheese: 1.08 (0.92, 1.25); Replacement of butter with cheese: 0.99 (0.94, 1.03); [underlined: Myocardial Infarction, HR (95% CI), per 1 svg, women only]; Replacement of whole-fat milk with:; - whole-fat yogurt: 0.83 (0.66, 1.03); - low-fat yogurt: 0.83 (0.69, 1.02); - cheese: 0.85 (0.76, 0.96); Replacement of low-fat milk with:; - low-fat yogurt: 0.88 (0.74, 1.06); - whole-fat yogurt: 0.87 (0.71, 1.05); - cheese: 0.90 (0.83, 0.96); Replacement of buttermilk with:; - low-fat milk: 1.00 (0.88, 1.15); - whole-fat milk: 1.06 (0.90, 1.24); - low-fat yogurt: 0.89 (0.71, 1.10); - whole-fat yogurt: 0.87 (0.69, 1.10); - cheese: 0.90 (0.78, 1.03); Replacement of whole-fat yogurt with cheese: 1.03 (0.84, 1.26); Replacement of low-fat yogurt with cheese: 1.01 (0.84, 1.22); Replacement of butter with cheese: 0.96 (0.90, 1.02) | Key confounders accounted for: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality, total energy intake; Key confounders NOT accounted for: Race and/or ethnicity (100% Danish); Other covariates accounted for: date of entry into study, red meat intake, processed meat intake, fish intake, vegetable intake, fruit intake, HTN, hypercholesterolemia, DM; Limitations: Exposure measured at baseline only; Funding: None received

a Abbreviations: β: beta; %tile: percentile; BMI: body mass index; BP: blood pressure; CE: cholesterol esters; CHO: carbohydrate; CI: confidence interval; CVD: Cardiovascular disease; CHD: Coronary heart disease; d: day; DBP: diastolic blood pressure; FFQ: food frequency questionnaire; g: grams; HDL: high-density lipoprotein; hx: history; LDL: low-density lipoprotein; mg: milligram; ml: milliliter; mmol: millimoles; mo: months; MI: Myocardial Infarction; MUFA: monounsaturated fatty acids; NA: not applicable; NIH: National Institutes of Health; NR: not reported; NS: non-significant; PCS: prospective cohort study; PUFA: poly-unsaturated fatty acids; RCT: Randomized controlled trial; REF: reference; SBP: systolic blood pressure; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SFA: Saturated fatty acids; SSB: sugar-sweetened beverages; TG: triglycerides; wk: week; wks: weeks; y: year

Table 34 Risk of bias for randomized controlled trials comparing dairy and dairy products with different amounts of total fat and risk of cardiovascular disease in adults^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (effect of assignment) | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of reported results | Overall risk of bias
Raziani, 2017^31^ | LOW | NOT APPLICABLE | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW
Nilsen, 2015^28^ | LOW | NOT APPLICABLE | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW
Alonso, 2009^25^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 35 Risk of bias for observational studies comparing dairy and dairy products with different amounts of total fat and risk of risk of cardiovascular disease^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Jamrozik, 2000^40^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Laursen, 2018^43^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Haring, 2014^38^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Hu, 1999^52^ | LOW | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Louie, 2013^47^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Patterson, 2013^49^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Dalmeijer, 2013^35^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Holmberg, 2009^39^ | VERY HIGH | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | VERY HIGH
Wang, 2021^50^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Laursen, 2019^44^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Laursen, 2022^45^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Kvist, 2020^42^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 36 Evidence examining the relationship between dairy consumption compared to food sources of unsaturated fatty acid, and risk of cardiovascular disease in adults^a^

Study and Participant Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Methodological Considerations
Haring, 2014^38^; PCS, United States, ARIC; Analytic N = 12,066; Participant characteristics:; - Age: ~53.8 (5.7)y; 45-64y; - Female: 56%; - Race and/or ethnicity: 77% White; 23% Black; - SEP: 79% High school graduates; - BMI 27.1 kg/m2; - Health Status: 29% HTN; Excluded participants with self-reported diabetes, fasting blood glucose ≥126 mg/dL, non-fasting blood glucose ≥200 mg/dL or use of diabetes medication, a history of myocardial infarction, stroke, heart failure, coronary bypass surgery, angioplasty or with missing data on covariates of interest. Participants that reported implausible energy intake or incomplete dietary information were excluded Current smoker: ~26% | Exposure and Comparators:; Continuous (1 svg/d substitution); - High-fat dairy; - Low-fat dairy; - Fish/seafood; - Eggs; - Nuts; - Legumes; Exposure assessment method: FFQ at baseline and ~6y follow-up (cumulative average); Baseline intake of study foods: Median: 0.4 svg/d of high-fat dairy, 0.4 svg/d of lowfat dairy, 0.4 svg/d of processed meat, 0.5 svg/d of red meat, 0.3 svg/d of poultry; Outcome(s): CHD (definite or probable MI, or CHD death); Outcome assessment methods and timing: Adjudicated using information from study visits, yearly telephone follow-up calls, review of hospital discharge lists and medical charts, death certificates, next-of-kin interviews, and physician-completed questionnaires at 22 y follow-up | [underlined: CHD per 1 svg/d substitution, HR (95% CI)]; Low-fat dairy for high-fat dairy: 0.93 (0.84, 1.02); [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy; Fish/seafood for high-fat dairy: 0.94 (0.75, 1.19); Low-fat dairy; Fish/seafood for low-fat dairy: 1.02 (0.80, 1.28); [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy; Eggs for high-fat dairy: 0.89 (0.75, 1.06); Nuts for high-fat dairy: 0.90 (0.78, 1.03); Legumes for high-fat dairy: 0.93 (0.73, 1.19); Low-fat dairy; Eggs for low-fat dairy: 0.96 (0.81, 1.14); Nuts for low-fat dairy: 0.97 (0.84, 1.11); Legumes for low-fat dairy: 1.01 (0.79, 1.28); [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy for processed meat: 1.04 (0.90, 1.20); High-fat dairy for red meat: 0.91 (0.74, 1.12); High-fat dairy for poultry: 1.12 (0.90, 1.40); Low-fat dairy for processed meat: 0.96 (0.84, 1.11); Low-fat dairy for red meat: 0.84 (0.68, 1.05); Low-fat dairy for poultry: 1.04 (0.83, 1.30) | Key confounders accounted for: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (all the food items in the table, fiber intake), total energy intake; Key confounders NOT accounted for: None; Other covariates accounted for: Study center, systolic blood pressure, use of antihypertensive and/or lipid lowering medication, HDL, total cholesterol, carbohydrate intake, magnesium intake; Limitations: Only Black and White participants are included, so the findings are not entirely generalizable. No preregistered data analysis plan; Funding: NHLBI/NIH; German Research Foundation; University of Wurzburg
Bernstein, 2010[underlined: ^34^]; PCS, United States, NHS; Analytic N = 84,136; Participant characteristics:; - Age: ~58 y; 30-55y; - Female: 100%; - Race and/or ethnicity: White; - SEP: 100% Nurses, health professionals; - BMI ~26 kg/m2; - Health Status: 34% history of high BP; 36% history of high cholesterol; Excluded participants with incomplete FFQ; implausible TEI; previously diagnosed cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of coronary artery bypass grafting) | Exposure and Comparators:; Continuous (1 svg/d substitution); - Poultry (chicken with and without skin, chicken sandwich, and chicken/turkey hot dog); - Fish (canned tuna, dark- and light-fleshed fish, and breaded fish); - Red meat (hamburger, beef hot dog, processed meat, and processed meat sandwich, bacon, beef/pork/lamb as a mixed and main dish); - Dairy, high-fat (whole milk, ice cream, hard cheese, full-fat cheese, cream, sour cream, cream cheese, butter); - Dairy, low-fat (skim/low-fat milk, 1% and 2% milk, yogurt, cottage and ricotta cheeses, low-fat cheese, sherbert); Exposure assessment method: Validated FFQ at baseline and every 4y (cumulative average); Baseline intake of study foods: Median ~1.06 svg/d of red meat and ~0.14 svg/d of poultry; Outcome(s): CHD (nonfatal myocardial infarction and fatal CHD); Outcome assessment methods and timing: Medical records, state vital records, National Death Index, postal system or report by a kin at 26 y follow-up | [underlined: CHD by 1 svg/d substitution]; High-fat dairy for fish: Data NR (figure showing >1 HR), P<0.05; Low-fat dairy for fish: Data NR (figure only), P=NS; [underlined: CHD by 1 svg/d substitution, RR (95% CI)]; High-fat dairy for poultry: Data NR (figure only), P=NS; Low-fat dairy for poultry: Data NR (figure only), P=NS; High-fat dairy for red meat: Data NR (figureshowing <1 HR), P<0.05; Low-fat dairy for red meat: 0.87 (0.81, 0.94) | Key confounders accounted for: Sex, age, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, trans fat), total energy intake, socioeconomic position; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: time period, menopausal status, parental history of early myocardial infarction, years of multivitamin use, vitamin E supplement use, aspirin use; Limitations: No preregistered data analysis plan; Funding: NIH; Unilever
Guasch-Ferré, 2022^36^; PCS, United States, NHS, HPFS; Analytic N = 92,383 (60,582 in NHS; 31,801 in HPFS); Participant characteristics:; - Age: ~56 y; 44-69 y (NHS), 44-79 y (HPFS); - Female: 0.66; - Race and/or ethnicity: 97% White; - SEP: 100% nurses or health professionals; - Mean BMI: ~25.5; - Health Status: Generally healthy; 19% HTN; 27% hypercholesterolemia; Excluded those with history of CVD or cancer at baseline; those with missing data for olive oil; those with implausible energy intake | Exposure and Comparators:; Continuous (10 g/d substitution); - Dairy, butter (added to foods and used for frying, sauteing, and baking) and dairy fat (source, % fat not specified); - Olive oil: used as salad dressing, added to food or bread, or used for baking and frying at home; 1 tbsp = 13.5 g; Exposure assessment method: Validated FFQ every 4 years; Baseline intake of study foods: NR; Outcome(s): CVD mortality; Outcome assessment methods and timing: Physician review of medical records, medical reports, autopsy reports, or death certificates at 28 y follow-up | [underlined: CVD-mortality per 10 g/d substitution, Pooled HR (95% CI)]; Olive oil for dairy fat: 0.92 (0.87, 0.97); Olive oil for butter: 0.93 (0.87, 0.99) | Key confounders accounted for: Sex, age, race and/or ethnicity, socioecononomic position (all nurses or health professionals, marital status, living alone), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, whole grains, red meat, nuts, soda, trans fat), TEI; Key confounders NOT accounted for: None; Other covariates accounted for: Family history of DM; family Hx MI; family Hx Cx; multivitamin use; aspirin use; menopausal status and hormone use (NHS); other types of fat (margarine, mayonnaise, other vegetable oils); butter (for dairy fat analyses); dairy fat (for butter analyses); Limitations: No preregistered data analysis plan; Funding: NIH
Guasch-Ferré, 2020^37^; PCS, United States, NHS, HPFS; Analytic N = 93,041 (61,181 in NHS; 31,797 in HPFS); Participant characteristics:; - Age: ~65 y; 26-69 y (NHS) and 44-79 y (HPFS); - Female: 66%; - Race and/or ethnicity: 97% White; - SEP: All nurses or health professionals; - BMI ~26 kg/m2; - Health Status: Generally healthy; 42% HTN; 51% hypercholesterolemia; Excluded those with cancer, heart disease, or stroke; missing data for olive oil; daily energy intake <600 or >3500 kcal for women, or <800 or >4200 kcal for men | Exposure and Comparators:; Continuous (5 g/d substitution); - Olive oil: used as salad dressing, added to food or bread, or used for baking and frying at home; 1 tbsp = 13.5 g; - Butter: added to foods and used for frying, sauteing, and baking; - Dairy fat: details NR; Exposure assessment method: Validated FFQ at baseline and every 4 years; Baseline intake of study foods: NR; Outcome(s): CVD, CHD, Stroke; Outcome assessment methods and timing: Physician review of medical records, medical reports, autopsy reports, or death certificates at 24 y follow-up | [underlined: CVD per 5 g/d substitution, Pooled HR (95% CI)]; Olive oil for butter: 0.95 (0.91, 1.00), P=0.06; Olive oil for dairy fat: 0.95 (0.92, 0.98), P<0.001; [underlined: CHD per 5 g/d substitution, Pooled HR (95% CI)]; Olive oil for butter: 0.94 (0.89, 1.01); Olive oil for dairy fat: 0.93 (0.89, 0.97); [underlined: Stroke per 5 g/d substitution, Pooled HR (95% CI)]; Olive oil for butter: 0.96 (0.89, 1.04); Olive oil for dairy fat: 0.98 (0.93, 1.04); Data NR for NHS and HPFS separately (figure only) | Key confounders accounted for: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, whole grains, red meat, nuts, soda, trans fat), TEI; Key confounders NOT accounted for: Socioeconomic position; Other covariates accounted for: Family history of diabetes, myocardial infarction, cancer; T2DM; HTN or antihypertensive medication use; hypercholesterolemia or cholesterol-lowering medication use; multivitamin or aspirin use; postmenopausal status and menopausal hormone use (women); other types of fat (e.g., margarine, mayonnaise, vegetable oils); Limitations: No preregistered data analysis plan; Funding: NIH
Brassard, 2017^6^; RCT-crossover, Canada; Analytic N = 92; Adequately powered: Yes; Study aims: To assess the impact of consuming equal amounts of SFA from cheese, butter vs. MUFA, PUFA and CHO on cardiometabolic risk factors; Participant characteristics:; - Age: 39.2 y; 18-65 y; - Female: 53%; - Race and/or ethnicity: 72% White; 8% Black; 8% Hispanic; 11% Asian; 2% Other; - SEP: NR; - BMI: 30.79 kg/m2; - Health Status: 100% Abdominal obesity; All participants with HDL below the age- and sex-specific 75th percentiles (≤1.34 and ≤1.53 mmol/L for men and women, respectively); Excluded individuals with high HDL-cholesterol concentrations, a history of CVD, type 2 diabetes, or monogenic dyslipidemia; the use of medications for hypertension, hyperlipidemia, or glycemic control; uncontrolled endocrine disorder such as hypothyroidism or hyperthyroidism; smoking; a Framingham-calculated CAD risk score >20%; any food allergies or aversion to foods that were included in the menu; particular nutritional habits such as vegetarianism; and women with menstrual irregularities including those who were experiencing perimenopause. Participants not allowed to use anti-inflammatory drugs. Included participants with waist circumference ≥94 and ≥80 cm for men and women, respectively, and have HDL-cholesterol concentrations below the age- and sex-specific 75th percentiles (≤1.34 and ≤1.53 mmol/L for men and women, respectively) | Intervention and Comparators:; - MUFA: diet rich in MUFA (5.8% SFA; 19.6% MUFA; 4.8% PUFA; 51.9% CHO); - PUFA: diet rich in PUFA (5.8% SFA; 12.6% MUFA; 11.5% PUFA; 51.9% CHO); - CHO: high CHO, low- fat (5.8% SFA; 12.6% MUFA; 4.8% PUFA; 58.9% CHO); - Cheese: 90 g/2500 kcal (12.6% SFA; 12.5% MUFA; 4.8% PUFA; 51.9% CHO); - Butter: 48.9 g/2500 kcal (12.4% SFA; 12.3% MUFA; 4.8% PUFA; 52% CHO); Intervention duration: 4 wk each (≥24d washout period); Other Group Differences: SFA in butter and cheese was matched.; Diets were identical in terms of energy, protein, cholesterol, sodium and fiber contents; calcium and potassium were higher in the cheese condition than the other 4.; Compliance: Yes; Participants filled checklist.; Excluded participants from the treatment phases where compliance was <80%; Compliance: 98.7% ± 2.4% after the exclusion of non-compliant subjects; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood measured twice on consecutive days at the end of each dietary phase. Mean of the two measurements was used | [underlined: LDL (mmol/L), Mean (SD)]; Cheese: 3.19 (0.81); Butter: 3.30 (0.84); MUFA: 3.03 (0.78); PUFA: 2.84 (0.69); Cheese vs. MUFA: P<0.05; Butter vs. MUFA: P<0.05; Cheese vs. PUFA: P<0.05 Butter vs. PUFA: P<0.05; [underlined: HDL (mmol/L), Mean (SD)]; Cheese: 1.10 (0.19); Butter: 1.11 (0.21); MUFA: 1.10 (0.19); PUFA: 1.10 (0.20) Cheese vs. MUFA;; Cheese vs. PUFA;; Butter vs. PUFA;; Butter vs. MUFA: P>0.05; [underlined: TG (mmol/L), Mean (SD)]; Cheese: 1.43 (0.70); Butter: 1.36 (0.73); MUFA: 1.38 (0.67); PUFA: 1.30 (0.62); Cheese vs. PUFA: P<0.05; Cheese vs. MUFA; Butter vs. PUFA;; Butter vs. MUFA: P>0.05; Results were also provided from ITT with similar findings; [underlined: SBP (mmHg), Mean (SD)]; Cheese: 109.9 (13.4); Butter: 109.0 (12.4); MUFA: 111.4 (12.9); PUFA: 109.9 (13.0); P (between group)>0.05; [underlined: DBP (mmHg), Mean (SD)]; Cheese: 70.0 (10.4); Butter: 68.9 (9.8); MUFA: 68.7 (9.8); PUFA: 68.8 (11.3); P (between group)>0.05; Results were also provided from ITT with similar findings; [underlined: LDL (mmol/L), Mean (SD)]; Cheese: 3.19 (0.81); Butter: 3.30 (0.84); CHO: 3.11 (0.79); Cheese vs. CHO: P<0.05; Butter vs. CHO: P<0.05; [underlined: HDL (mmol/L), Mean (SD)]; Cheese: 1.10 (0.19); Butter: 1.11 (0.21); CHO: 1.06 (0.19); [underlined: Cheese vs. CHO: P<0.05]; [underlined: Butter vs. CHO: P<0.05]; [underlined: TG (mmol/L), Mean (SD)]; Cheese: 1.43 (0.70); Butter: 1.36 (0.73); CHO: 1.46 (0.71); Butter vs. CHO: P<0.05; Cheese vs. CHO: P>0.05; Results were also provided from ITT with similar findings; [underlined: SBP (mmHg), Mean (SD)]; Cheese: 109.9 (13.4); Butter: 109.0 (12.4); CHO: 109.8 (12.6); P (between group)>0.05; [underlined: DBP (mmHg), Mean (SD)]; Cheese: 70.0 (10.4); Butter: 68.9 (9.8); CHO: 69.9 (10.0); P (between group)>0.05; Results were also provided from ITT with similar findings; [underlined: LDL (mmol/L), Mean (SD)]; Cheese: 3.19 (0.81); Butter: 3.30 (0.84); P<0.05; [underlined: HDL (mmol/L), Mean (SD)]; Cheese: 1.10 (0.19); Butter: 1.11 (0.21); P>0.05; [underlined: TG (mmol/L), Mean (SD)]; Cheese: 1.43 (0.70); Butter: 1.36 (0.73); P<0.05; Results were also provided from ITT with similar findings; [underlined: SBP (mmHg), Mean (SD)]; Cheese: 109.9 (13.4); Butter: 109.0 (12.4); P>0.05; [underlined: DBP (mmHg), Mean (SD)]; Cheese: 70.0 (10.4); Butter: 68.9 (9.8); P>0.05; Results were also provided from ITT with similar findings | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: High drop-out rates; Funding: Fondation du Centre Hospitalier Universitaire de Québec – Université Laval; Green Fund of the Government of Québec
Karvonen, 2002^13^; RCT-crossover, Finland; Analytic N = 31; Adequately powered: No; Study aims: To investigate the effect of rapeseed oil-based cheese on serum total and lipoprotein lipids vs. milk-fat-based cheese; Participant characteristics:; - Age: 52.9 (9.2) y; 25-65y; - Female: 55%; - Race and/or ethnicity: NR; - SEP: NR; - BMI 25.9 (2.9) kg/m2; - Health Status: 100% Elevated cholesterol (mild to moderate); TC between 5.0 and 8.0 mmol/L; TG <3.0 mmol/L; normal liver, kidney and thyroid Fx; All with mild to moderately elevated serum cholesterol (TC between 5.0 and 8.0 mmol/L); TG <3.0 mmol/L; normal liver, kidney and thyroid Fx. Excluded those with or who: taking lipid lowering Rx; history of unstable CAD (MI, CABG, PTCA) within previous 6 months; Hx DM, TIA, or malignant disease; alcohol use of >50g/day; irregular eating habits, food allergies, or other difficulties in consuming test products | Intervention and Comparators:; - Rapeseed oil cheese: 65g of low-fat cheese containing 17% rapeseed oil and no other fat; providing 282 kcal, 17g fat, 0.7g SFA, 10.1g MUFA, 5.5g PUFA, 30g PRO, and 1.8g CHO per 100g; - Milk-fat cheese (control): 65g of “normal, moderate-fat, milk-fat-based cheese”; providing 335 kcal, 24g fat, 15.6g SFA, 5.0g MUFA, 0.5g PUFA, 27g PRO, and 1.8g CHO per 100g; Intervention duration: 4 wk (no washout); Other Group Differences: Energy of cheese not matched, but no significant difference in total energy of the diet between control (1950 kcal) and rapeseed-oil (2050kcal) cheese conditions. Total fat, SFA > in control condition MUFA, PUFA, PRO > in rapeseed cheese condition No difference in CHO; Compliance: Yes, average total amount of test cheese consumed was 65.0 (0.0) g/day rapeseed oil-based cheese and 64.6 (2.0) g/day control cheese; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood collection at baseline, 2wk, and 4wk | [underlined: LDL (mmol/L), Mean (SD) at 2 wk, 4 wk]; Rapeseed oil cheese: 3.85 (0.49), 3.95 (0.52), P=NS; Milk fat cheese: 4.19 (0.70), 4.23 (0.47), P=NS; Between group: difference at 4wk, P=0.002; Between group: change (95% CI) at 4wk; Absolute: −0.28 (0.42), 95% CI: −0.43, 0.13; Percent: −6.4 (9.9), 95% CI: −10.0, −2.8; [underlined: HDL (mmol/L), Mean (SD)]; Within group: 2wk, 4wk; Rapeseed oil cheese: 1.25 (0.37), 1.31 (0.40); Milk fat cheese: 1.29 (0.38), 1.35 (0.42); Between group: difference at 4wk: P=NS; Between group: change at 4wk; Absolute: −0.04 (0.14), 95% CI: −0.09, 0.01; Percent: - 2.3 (8.7), 95% CI: −5.4, 0.9; [underlined: TG (mmol/L), Mean (SD)]; Within group: 2wk, 4wk; Rapeseed oil cheese: 1.39 (0.55), 1.57 (0.69); Milk fat cheese: 1.51 (0.70), 1.57 (0.77); Between group: difference at 4wk: P=NS; Between group: change at 4wk; Absolute: 0 (0.51), 95% CI: −0.18, 0.19; Percent: 6.8 (35.5), 95% CI: −6.2, 19.8; [underlined: SBP (mmHg), Mean (SD)]; Baseline: 131 (19); Milk fat cheese vs Rapeseed oil cheese: Data NR, P=NS; [underlined: DBP (mmHg), Mean (SD)]; Baseline: 83 (10); Milk fat cheese vs Rapeseed oil cheese: Data NR, P=NS | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: No preregistered data analysis plan; Funding: Mildola Ltd and Kyronmaan Juustomestarit Ltd (Finland)
Pancheco, 2022^48^; PCS, United States, NHS, HPFS; Analytic N = 110,487; Participant characteristics:; - Age: 52.87 (Men); 52.48 (Women); - Female: 62%; - Race and/or ethnicity: 97% White; - SEP: 100% nurses or health professionals; - BMI: 25.5 kg/m2 (men); 25.3 kg/m2 (women); - Health Status: Generally healthy; LDL greater than 130 mg/dl; mean 167 (28) mg/dl; - HDL: 48(11) mg/dl; - TG: 148 (64) mg/dl; - TC: 245 (33) mg/dl; - VLDL: 29 (12) mg/dl; Excluded participants with a baseline history of heart disease, stroke, or cancer. Excluded participants with missing information on avocado intake and implausible energy intake. | Exposure and Comparators:; - Avocado, 1/2 serving substitution; - Cheese, regular and low-fat or light (cottage or ricotta, cream, and all other cheeses including hard); - Butter; Exposure assessment method: FFQ assessed every 4 y; Baseline intake of study foods: NR; Outcome(s): Total CVD: composite of fatal CHD and nonfatal myocardial infarction and fatal and nonfatal stroke; Total CHD: Fatal CHD and nonfatal myocardial infarction; Total stroke: Fatal and nonfatal ischemic, hemorrhagic, and unknown subtypes of stroke; Outcome assessment methods and timing: Non-fatal: Self-reported + medical records reviewed by physicians; Fatal: National Death Index, family members response in questionnaire, report from participant’s professional organizations at 30 y (Median f/u for men: 13.3; women: 14.2 y) followup | [underlined: CVD, HR (95% CI)]; Replacing butter with avocado: 0.78 (0.63, 0.96); Replacing cheese with avocado: 0.87 (0.77, 0.98); [underlined: CHD, HR (95% CI)]; Replacing butter with avocado: 0.69 (0.53, 0.90); Replacing cheese with avocado: 0.75 (0.65, 0.87); [underlined: Stroke, HR (95% CI)]; Replacing butter with avocado: 0.89 (0.63, 1.25); Replacing cheese with avocado: 1.07 (0.90, 1.28) | Key confounders accounted for: Sex, Age, Race/ethnicity, SEP, Physical activity, Anthropometry, Smoking, Alcohol, Diet quality, Total energy; Key confounders NOT accounted for: None; Other covariates accounted for: Family history of diabetes, MI, baseline diabetes; baseline hypertension or antihypertensive medication use; baseline hypercholesterolemia or cholesterol-lowering medication use; multivitamin use; aspirin use; red and processed meat, fruits and vegetables (excluding avocado), nuts, soda (caloric and low or noncaloric), whole grains, eggs, tortilla (whole and chips), breads, cheese intakes; trans-fat, and mutually adjusted for other types of fat-containing foods; Limitations: % fat in the dairy foods is not specific. Participants are well-educated and mostly White, so the findings may not be generalizable. Multiple comparisons were not adjusted/accounted for.; Funding: NIH, Harvard Chan Yerby Fellowship

a Abbreviations: β: beta; %tile: percentile; BMI: body mass index; BP: blood pressure; CE: cholesterol esters; CHO: carbohydrate; CI: confidence interval; d: day; DBP: diastolic blood pressure; FFQ: food frequency questionnaire; g: grams; GWG: gestational weight gain; HDL: high-density lipoprotein; hx: history; LDL: low-density lipoprotein; mg: milligram; ml: milliliter; mmol: millimoles; mo: months; MUFA: monounsaturated fatty acids; NA: not applicable; NIH: National Institutes of Health; NR: not reported; NS: non-significant; PCS: prospective cohort study; PUFA: poly-unsaturated fatty acids; RCT: Randomized controlled trial; REF: reference; SBP: systolic blood pressure; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SFA: Saturated fatty acids; SSB: sugar-sweetened beverages; TG: triglycerides; wk: week; wks: weeks; y: year; YHEI: Youth Health Eating Index

Table 37 Risk of bias for randomized controlled trials examining dairy compared to food sources of unsaturated fatty acids and risk of cardiovascular disease in adults^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (effect of assignment) | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall
Karvonen, 2002^13^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Brassard, 2017^6^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 38 Risk of bias for observational studies examining dairy compared to food sources of unsaturated fatty acids and risk of cardiovascular disease^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurem ent | Selection of the reported result | Overall
Haring, 2014^38^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bernstein, 2010^34^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Guasch-Ferré, 2022^36^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Guasch-Ferré, 2020^37^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Pancheco, 2022^48^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 39 Evidence examining the relationship between butter consumption and risk of cardiovascular disease in adults^a^

Study and Participant Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Methodological Considerations
Denke, 2000^1^; RCT-crossover, United States; Analytic N = 226 (46 families: 92 adults; 126 children); Adequately powered: NR; Study aims: To investigate individual variations in cholesterol in response to margarine or butter; Participant characteristics:; - Age: Adults: 41(4) y; Children: 12 (4); - Female: 48%; - Race and/or ethnicity: 85% White; 7% Black; 4% Hispanic American; 2% American Indian; 2% Asian American; - SEP: NR; - Adult BMI: 28.8 (6.5); - Children BMI: 19.3 (4.3); - Health Status: Generally overweight/Obesity; Excluded families with < 2 biological parents and < 2 biologically related children >5 y. | Intervention and Comparators:; - Butter: 50.6% SFA (total diet: 16g SFA; 35g total fat); - Margarine: 80% fat by weight with 38.7% cis-PUFA and 7.5 trans-fatty acids (total diet: 9g SFA; 37g total fat); Intervention duration: 5 wk; Other Group Differences: Significantly different: Dietary cholesterol, protein, SFA and cholesterol-raising fatty acids higher in butter intake period, fat, PUFA, trans-fat higher in margarine intake period.; NS: Total energy, MUFA, CHO; Compliance: Yes, “Excellent” adherence with 88% and 83% of test fat delivered during margarine or butter being consumed; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood lipids during the last 2 wks of each dietary period | [underlined: LDL (mg/dL), Mean (SD)]; Butter: 131 (32); Margarine: 116 (27); Difference (95% CI): −15.7 (−18.8, −12.6), P<0.001; [underlined: HDL (mg/dL), Mean (SD)]; Butter: 46 (12); Margarine: 46 (12); Difference (95% CI): −0.1 (−1.2, 0.9), P=0.83; [underlined: TG (mg/dL), Mean (SD)]; Butter: 135 (95); Margarine: 125 (76); Difference (95% CI): −10.8 (−20.7, −0.9), P=0.03 | Key confounders accounted for: NA; Other covariates accounted for: Age, BMI, ad libitum LDL levels, apoE genotype, change in serum fatty acid CE levels; Limitations: Participants were not blinded; No power calculation; No analytic plan; Funding: United Soybean Board, National Association of Margarine Manufacturers, United States Public Health Service grant
Lichtenstein, 1999^15^; RCT-crossover, United States; Analytic N = 36; Adequately powered: NR; Study aims: To investigate the effects of diet with margarine and vegetable shortening (vs. butter) on cholesterol levels; Participant characteristics:; - Age: 63 (6) y; - Female: 50%; - Race and/or ethnicity: NR; - SEP: NR; - Mean BMI: 27.4(3.0); - Health Status: 100% hypercholesterolemia (mild); 100% LDL >130 mg/dL; Excluded participants with LDL ≤130 mg/dL (borderline high) and participants with hypertension that were taking beta-blockers | Intervention and Comparators: Each diet provided 30% calories as fat, with 2/3rd of fat contributed by:; - Soybean oil (25 g SFA per 100 g of fat); - Semiliquid margarine (27 g SFA per 100 g); - Soft margarine (25.2 g SFA per 100 g); - Shortening (29.3 g SFA per 100 g); - Stick margarine (27 g SFA per 100 g); - Butter: 16.7 g SFA; 28g total fat; Intervention duration: 35 d; Other Group Differences: PUFA was higher in soybean oil, semiliquid margarine, soft margarine, when compared to shortening, stick margarine and butter; Compliance: Yes, controlled feeding. Participants ate one meal on site.; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood lipids at 28 d after baseline | [underlined: LDL (mg/dL) (All)]; Soybean oil: 154 (28); Semiliquid margarine: 155 (27); Soft margarine: 159 (26); Shortening: 164 (28); Stick margarine: 168 (30); Butter: 177 (32); P<0.05: Soybean oil vs. Butter; P<0.05: Semiliquid margarine vs. Butter; P<0.05: Soft margarine vs. Butter; P<0.05: Shortening vs. Butter; P<0.05: Stick margarine vs. Butter; [underlined: LDL, mg/dL (Women)]; Soybean oil: 153 (32); Semiliquid margarine: 155 (25); Soft margarine: 164 (29); Shortening: 164 (29); Stick margarine: 169 (29); Butter: 177(31); P<0.05: Soybean oil vs. Butter; P<0.05: Semiliquid margarine vs. Butter; P<0.05: Soft margarine vs. Butter; All other comparisons to butter: P=NS; [underlined: LDL, mg/dL (Men)]; Soybean oil: 155 (25); Semiliquid margarine: 156 (30); Soft margarine: 154 (23); Shortening: 164 (28); Stick margarine: 167 (32); Butter: 177 (33); P<0.05: Soybean oil vs. Butter; P<0.05: Semiliquid margarine vs. Butter; P<0.05: Soft margarine vs. Butter; All other comparisons to butter: P=NS; [underlined: HDL, mg/dL (All)]; Soybean oil: 43(9); Semiliquid margarine: 43(10); Soft margarine: 43(9); Shortening: 43(9); Stick margarine: 42(9); Butter: 45(10); P<0.05: Stick margarine vs. Butter; All other comparisons to butter: P=NS; [underlined: HDL, mg/dL (Women)]; Soybean oil: 47(9); Semiliquid margarine: 47(10); Soft margarine: 47(9); Shortening: 45(10); Stick margarine: 45(9); Butter: 50(10); P<0.05: Shortening vs. Butter; P<0.05: Stick margarine vs. Butter; All other comparisons to butter: P=NS; [underlined: HDL, mg/dL (Men)]; Soybean oil: 40(7); Semiliquid margarine: 40(8); Soft margarine: 39(7); Shortening: 40(8); Stick margarine: 39(8); Butter: 40(9); All comparisons to butter: P=NS; [underlined: TG, mg/dL (All)]; Soybean oil: 143 (64); Semiliquid margarine: 133 (54); Soft margarine: 149 (78); Shortening: 147 (53); Stick margarine: 156 (68); Butter: 146 (57); All comparisons to butter: P=NS; [underlined: TG, mg/dL (Women)] Soybean oil: 131 (51); Semiliquid margarine: 133 (53); Soft margarine: 138 (52); Shortening: 145 (58); Stick margarine: 151 (64); Butter: 138 (46); All comparisons to butter: P=NS; [underlined: TG, mg/dL (Men)]; Soybean oil: 155 (74); Semiliquid margarine: 134 (56); Soft margarine: 159 (98); Shortening: 148 (49); Stick margarine: 161 (74); Butter: 154 (66); All comparisons to butter: P=NS | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Lipids were drawn (28 d) prior to end of intervention period (35 d); Funding: NIH, USDA
Cox, 1998^8^; RCT-crossover, New Zealand; Analytic N = 37; Adequately powered: NR; Study aims: To determine plasma levels of lathosterol, lipids, lipoproteins and apolipoproteins during diets rich in butter, coconut fat and safflower oil.; Participant characteristics:; - Age: 35 (9) y in men and 39 (9) y in women; 19-72 y; - Female: 41%; - Race and/or ethnicity: All Pacific Islanders; - SEP: NR; - BMI 29.7 (3.5) kg/m2 in men, 26.8 (5.4) kg/m2 in women; - Health Status: Healthy; Excluded those with plasma cholesterol <4.2 or >7.5 mmol/L and plasma TG ≥3 mmol/L | Intervention and Comparators:; - Coconut oil: participants were instructed to eat coconut cream, coconut bread, monounsaturated margarine, coconut, fish, meat cheese, chicken, fruit and vegetables, rice, noodles, trim milk and other low fat dairy products and not to eat butter, cream, other margarines, chicken skin, deep-fried takeaway foods and vegetable oils (providing 39g fat from coconut oil to give an intake of ~17 g lauric acid); - Safflower oil (MUFA/PUFA): participants were instructed to eat polyunsaturated margarine, safflower oil, safflower bread, cheese, meat, fish, chicken, fruit and vegetables, rice, noodles, trim milk, low fat dairy products and not to eat butter, cream, coconut cream and products, cream, reduced fat cream and deep-fried takeaway foods (providing 24g fat from safflower oil to give an intake of ~17 g linoleic acid); - Butter: participants were instructed to eat butter, cream, butter bread, cheese, meat, fish, chicken, fruit and vegetables, rice, noodles, full cream milk and milk products and were instructed not to eat coconut cream or products, margarine and cooking oils (providing 39g fat from butter plus fat from palmitic acid-rich foods to give an intake of ~17g palmitic acid); Intervention duration: 6 wk each (no washout); Other Group Differences: All diets had target value of 84g total fat and were designed to provide ~17% protein, 47% carbohydrate and 36% fat as a fraction of TEI; Compliance: Assessed but NR; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood collection at baseline and at week 4 and week 6 of each 6wk period (reported results for 4wk values, noting there was no significant change from 4 to 6wk in cholesterol or TG) | [underlined: LDL (mmol/L), Mean (SD) at 4wk]; Butter: 4.08 (0.89); Safflower oil: 3.50 (0.84); Coconut oil: 3.79 (0.75); Butter vs Coconut oil: P<0.01; Butter vs Safflower oil: P<0.01; [underlined: HDL (mmol/L), Mean (SD) at 4wk]; Butter: 1.16 (0.24); Safflower oil: 1.06 (0.21); Coconut oil: 1.21 (0.27); Butter vs Coconut oil: P=NS; Butter vs Safflower oil: P<0.01; [underlined: TG (mmol/L), Mean (SD) at 4wk]; Butter: 1.86 (0.89); Safflower oil: 1.77 (1.25); Coconut oil: 1.61 (0.93); Butter vs Coconut oil: P=NS; Butter vs Safflower oil: P=NS | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Inadequate information on randomization; Order of conditions was sequential for all participants, not counterbalanced; Outcomes measured at week 4 of the 6wk intervention; No power calculation; No preregistered data analysis plan; Funding: Health Research Council of New Zealand; Anderson Telford Trust
Chisholm, 1996^7^; RCT-crossover, New Zealand; Analytic N = 49; Adequately powered: No; Study aims: To examine the effect on lipid and lipoprotein concentrations when butter or an unsaturated margarine is used for cooking or spreading in a reduced fat diet.; Participant characteristics:; - Age: 46.8 (11.6) y; - Female: 71%; - Race and/or ethnicity: NR; - SEP: NR; - BMI 26.4 (3.8) kg/m2; - Health Status: 100% with polygenic hypercholesterolemia/hyperlipidaemia; Excluded those with familial or secondary hyperlipidemia or taking drugs known to influence metabolism | Intervention and Comparators:; - Butter: 12% SFA, 8% MUFA, 3% PUFA (12% total energy from SFA; 26% energy from total fat); - Canola oil-based margarine: 6% SFA, 11% MUFA, 7% PUFA (6% total energy from SFA; 26% energy from total fat); Intervention duration: 6 wk (5 wk washout); Other Group Differences: None; Compliance: Yes, reported nutrient intakes from 4d diet records with consistent with prescribed diets and measuring TG; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood collection at baseline, after 5wk washout, and after each 6wk intervention period | [underlined: LDL (mmol/L)]; Within group: Mean (SD) at baseline, 6wk; Margarine: 4.38 (0.74), 3.82 (0.74); Butter: 4.44 (0.74), 4.21 (0.78); Between group: Mean difference (95% CI); Margarine minus Butter: 0.32 (0.09, 0.56), P=0.009; [underlined: HDL (mmol/L)]; Within group: Mean (SD) at baseline, 6wk; Margarine: 1.26 (0.30), 1.24 (0.30); Butter: 1.27 (0.31), 1.26 (0.29); Between group: Mean difference (95% CI); Margarine minus Butter: 0.01 (−0.04, 0.07), P=0.482; [underlined: TG (mmol/L)]; Within group: Mean (SD) at baseline, 6wk; Margarine: 1.85 (1.17), 1.85 (1.11); Butter: 1.91 (1.01), 1.80 (0.99); Between group: Mean difference (95% CI); Margarine minus Butter: −0.10 (−0.38, 0.16), P=0.439 | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Methods for randomization and concealment NR; No power calculation; Not all participants that enrolled completed the study and it is unclear why they dropped out. Trial registry did not include data analysis plan; Funding: National Heart Foundation of New Zealand
Wood, 1993^24^; RCT-crossover, United States; Analytic N = 38; Adequately powered: No; Study aims: To examine the effect of diets containing 50% of fat calories from butter, butter enriched with mono- and polyunsaturated fatty acids, and margarines with and without trans fatty acids on the serum lipids of healthy men; Participant characteristics:; - Age: 42 (8) y; 30-60 y; - Female: 0%; - Race and/or ethnicity: NR; - SEP: All university faculty and staff; - Weight 181 (21) lbs; - Health Status: All normotensive; none with history of coronary vascular disease, hypercholesterolemia, or diabetes; Excluded those on prescribed medication. | Intervention and Comparators:; - Butter-olive oil: 1.8% salt, equal parts butter and olive oil (44% SFA, 44.5% MUFA, 11% PUFA); - Butter-sunflower oil: 1.8% salt, equal parts butter and sunflower oil (37% SFA, 21% MUFA, 36.5% PUFA); - Hard margarine: 3.0% salt, partially hydrogenated vegetable oil (22% SFA, 72% MUFA, 3.5% PUFA); - Soft margarine: 1.8% salt, 87% sunflower oil and 13% modified palm and palm kernel oil (22% SFA, 14% MUFA, 61% PUFA); The test fats were supplied to participants as spreads (1-lb containers, cookies, ice cream, and milk where the test fats replaced the fats normally present.; Butter: 1.8% salt (65% SFA, 26% MUFA, 4% MUFA); 40% energy from fat, 60% of fat from butter; Intervention duration: 12 wk (6 wk washout); Other Group Differences: NS difference in protein intake for any diet; Compliance: Yes, based on % of calories consumed from the test fats, similar average compliance on all diets. 24-hr diet recalls were used as a cross-check on food consumption.; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood collection weekly after baseline (mean of 5th and 6th week used in analysis) | [underlined: LDL (mg/dL), Mean (SD) at 5th and 6th week]; Butter: 146 (29); Butter-sunflower: 135 (27); Butter-olive oil: 139 (28) Hard margarine: 134 (25); Soft margarine: 126 (25); Butter > All groups: P<0.05; [underlined: HDL (mg/dL), Mean (SD) at 5th and 6th week]; Butter: 47 (10); Butter-sunflower: 46 (10) Butter-olive oil: 47 (11); Hard margarine: 45 (9); Soft margarine: 45 (10); Butter vs All groups: P=NS for all pairwise comparisons; [underlined: TG (mg/dL), Mean (SD) at 5th and 6th week]; Butter: 109 (53); Butter-sunflower: 107 (50); Butter-olive oil: 108 (46) Hard margarine: 114 (44); Soft margarine: 100 (38); Butter vs All groups: P=NS for all pairwise comparisons | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Methods for randomization and concealment NR; No power calculation; Trial registry did not include data analysis plan; Funding: Dairy Bureau of Canada
Liu, 2017^46^; PCS, United States, WHI (Women’s; Health Initiative); Analytic N = 69,223; Participant characteristics:; - Age: 63.1 (7.3) y; 50-79 y; - Female: 100%; - Race and/or ethnicity: 85% White; 7% Black; 4% Hispanic; 3% Asian; 1% Other; - SEP: 32% post-graduate degree, 20% with annual household income ≥$75,000 57% with overweight or obesity; - Health Status: Generally healthy and without stroke, cancer, or diabetes; 21% HTN, 2% treated hypercholesterolemia; 49% family history of MI; 39% hysterectomy; Excluded those with MI, CABG, percutaneous transluminal coronary angioplasty, stroke, cancer, diabetes, implausible energy intake (<500 or >5000 kcal/d) | Exposure and Comparators:; - Butter: 51% SFA, 21% MUFA, 3% PUFA, 3% trans fatty acids; 1 svg = 1 tsp (4.73 g); - Stick Margarine: 15% SFA, 39% MUFA, 24% PUFA, 15-21% trans fatty acids; 1 svg = 1 tsp (4.73 g); - Tub Margarine: 14% SFA, 36% MUFA, 27% PUFA, 5% trans fatty acids; 1 svg = 1 tsp (4.73 g); - Low-fat Margarine: 3-12% SFA, 7-30% MUFA, 8-26% PUFA, 1-17% trans fatty acids; 1 svg = 1 tsp (4.73 g); Exposure assessment method: Four questions from FFQ at baseline and year 3 (used cumulative average in analysis); Baseline intake of study foods: NR; Outcome(s): MI, Total CHD (defined as first occurrence of MI, CABG, percutaneous transluminal coronary angioplasty), Ischemic stroke, Atherosclerosis-related CVD (included MI, incident CHD, CHDrelated death, and ischemic stroke); Outcome assessment methods and timing: Medical records ascertained by trained physician adjudicator; annually reviewed at 13.2 (4.3) y follow-up | [underlined: MI by 1 tsp/d substitution, HR (95% CI)]; Total margarine for butter: 1.0 (0.94, 1.1); Stick margarine for butter: 1.0 (0.97, 1.1); Tub margarine for butter: 0.95 (0.89, 1.0); Low-fat margarine for butter: 0.98 (0.90, 1.1); [underlined: Total CHD by 1 tsp/d substitution, HR (95% CI)]; Total margarine for butter: 1.1 (1.0, 1.1); Stick margarine for butter: 1.0 (0.99, 1.1); Tub margarine for butter: 1.0 (0.97, 1.1); Low-fat margarine for butter: 1.0 (0.91, 1.1); [underlined: Ischemic stroke by 1 tsp/d substitution, HR (95% CI)]; Total margarine for butter: 1.1 (0.97, 1.2); Stick margarine for butter: 1.1 (0.97, 1.1); Tub margarine for butter: 1.0 (0.92, 1.1); Low-fat margarine for butter: 1.0 (0.97, 1.1); [underlined: Atherosclerosis-related CVD by 1 tsp/d substitution, HR (95% CI)]; Total margarine for butter: 1.1 (1.0, 1.1); Stick margarine for butter: 1.0 (0.99, 1.1); Tub margarine for butter: 1.0 (0.97, 1.0); Low-fat margarine for butter: 1.0 (0.97, 1.1) | Key confounders accounted for: Sex, age, race and/or ethnicity, socioeconomic position (income), physical activity, anthropometry, smoking, alcohol, diet quality (AHEI), total energy intake; Key confounders NOT accounted for: None; Other covariates accounted for: Region, HTN, family history of MI, postmenopausal hormone use, aspirin use, hysterectomy; Limitations: No preregistered data analysis plan; potential misclassification of butter and margarine when both consumed; although two measurements of diet, relatively short period apart in comparison to the long follow-up; Funding: NHLBI
Engel, 2015^10^; RCT-crossover, Denmark; Analytic N = 47; Adequately powered: Yes; Study aims: To investigate the effect of a diet with a moderate amount of butter or refined olive oil, with equal amounts of fat content, and habitual diet measured in the run-in period on risk markers of CVD and fasting serum lipids in healthy participants.; Participant characteristics:; - Age: 40.4 (14.8) y; 20-70 y; - Female: 70%; - Race and/or ethnicity: NR; - SEP: NR; - BMI 23.5 (2.5) kg/m2; - Health Status: Generally healthy; Mean SBP, 116 (8.3);; - Mean DBP, 72 (6.4); 5% smokers; Excluded those with current of previous CVD, DM, other severe chronic disease; BMI >32 kg/m2; >70y old; pregnant; excessive physical activity (>10 hr/wk); blood donations; use of supplements, lipid-lowering agents, medications that could affect study outcomes; known or suspected abuse of drugs, medication, or alcohol; inability to follow protocol | Intervention and Comparators:; - Olive oil: refined olive oil (baked into a bread roll, providing ~16% SFA based on sum of 6:0-18:0) to replace ~4.5% of daily energy intake after a 2wk run-in period of the habitual diet; - Butter: butter produced from cow’s milk (baked into a bread roll, providing ~63% SFA based on sum of 6:0-18:0) to replace ~4.5% of daily energy intake after a 2wk run-in period of the habitual diet; Intervention duration: 5 wk after a 2wk run-in (10d washout); Other Group Differences: Butter significantly higher in SFA; no other differences between conditions for total energy, %energy from fat, g fat, MUFA, PUFA, CHO, PRO.; Compliance: Yes, test food provided and collected weekly for weighing to ensure adherence; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood collection after run-in and each 5wk period | [underlined: LDL (mmol/L), Mean (SD) after various periods]; Run-in: 2.88 (0.81); Butter: 3.04 (0.86); Olive oil: 2.87 (0.86); Butter vs olive oil: P<0.05; HDL (mmol/L), Mean (SD) after various periods; Run-in: 1.69 (0.39); Butter: 1.75 (0.41); Olive oil: 1.73 (0.39); Butter vs olive oil: P=NS; [underlined: TG (mmol/L), Mean (SD) after various periods]; Run-in: 1.0 (0.35); Butter: 1.0 (0.35); Olive oil: 0.93 (0.38); Butter vs olive oil: P=NS | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: None; Funding: Danish Dairy Research Foundation; Arla Foods (Denmark);; AarhusKarlshamn (Denmark)
Morillas-Ruiz, 2014^19^; RCT-crossover, Spain; Analytic N = 53; Adequately powered: Yes; Study aims: To assess the effect of three types of fat (SFA, PUFA, MUFA) ingested at breakfast (as butter, margarine, and olive oil) on plasma levels of LDL, HDL, TG; Participant characteristics:; - Age: 63.5(2.5) y; - Female: 100%; - Race and/or ethnicity: 100% White; - SEP: NR; - BMI: 27.8(0.6) kg/m2; - Health Status: 27% arterial hypertension; 13% diabetes mellitus; 38% hypercholesterolemia; 17% history of CVD; 73% overweight/obesity; Post-menopausal women | Intervention and Comparators:; - Butter: 20g of butter (providing 81.1g fat per 100g food: 51.4g SFA; 21g MUFA; 3g PUFA and 215 mg cholesterol); - Margarine: 20 g of margarine (providing 60g fat per 100g food: 12.8 g SFA; 15.3 g MUFA; 29.2 g PUFA; 0 mg cholesterol); - Olive oil: 20 g of virgin olive oil (providing 99.9g fat per 100g food: 14.5 g SFA; 71 g MUFA; 10g PUFA; 0 mg cholesterol); All groups consumed fat as part of nonisocaloric breakfast, which consisted of 200mL semi-skimmed milk, 18g soluble coffee (1 monodose sachet), 8g of sugar (1 monodose sachet), and toasted white bread (2 toasts of 10g per unit); Washout breakfast contained 200mL pineapple juice and 50g peach jam instead of butter, margarine, or virgin olive oil; Intervention duration: 30 d (45d washout); Other Group Differences: Diet not isocaloric.; Compliance: NR; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood collection at baseline and after each 1mo period | [underlined: LDL (mg/dL), Mean (SEM)]; Within group: Baseline, 1mo; Butter: 118.70 (3.85), 120.89 (4.01); Margarine: 121.02 (3.75), 107.85 (3.10), P<0.0001; Olive oil: 113.20 (3.66), 111.00 (4.76); Between groups at 1mo: P=0.042; [underlined: HDL (mg/dL), Mean (SEM)]; Within group: Baseline, 1mo; Butter: 63.10 (1.40), 68.35 (1.85), P<0.0001; Margarine: 65.04 (1.66), 68.80 (1.78), P<0.0001; Olive oil: 66.78 (1.91), 67.58 (1.85); Between groups at 1mo: P=NS; [underlined: TG (mg/dL), Mean (SEM)]; Within group: Baseline, 1mo; Butter: 98.56 (5.64), 94.46 (5.69); Margarine: 90.47 (6.34), 89.11 (5.24); Olive oil: 91.78 (6.28), 88.73 (6.10); Between groups at 1mo: P=NS | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Adherence was not reported. Details about randomization is unclear; No preregistered data analysis plan; Funding: Catholic University of San Antonio
Mohammadifard, 2013^27^; RCT-parallel, Iran; Analytic N = 206 (hydrogenated, N=41; unhydrogenated, N=43; ghee, N=39; blended oil, N=42; soft margarine, N=41); Adequately powered: NR; Study aims: To assess the effect of ghee, unhydrogenated oil, blended oil, soft margarine or hydrogenated oil on serum lipid profile.; Participant characteristics:; - Age: 34.8 (11.4)y; 20-60y; - Female: 57%; - Race and/or ethnicity: 100% Iranian; - SEP: 37.8% illiterate; - BMI ~26 kg/m2; - Health Status: Generally healthy; Excluded those with HTN, CVD, diabetes, BMI ≥35 kg/m2, total cholesterol ≥240 mg/dl, TG ≥400 mg/dl, LDL ≥160 mg/dl, HDL ≤40 mg/dl | Intervention and Comparators:; - Ghee (replaced regular hydrogenated oil, amount varied by participant’s usual hydrogenated oil intake); - Soft margarine; - Unhydrogenated oil; - Hydrogenated; - Blended oil; Intervention duration: 40 d; Other Group Differences: NR; Compliance: No; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood collection at baseline and post-intervention | [underlined: LDL (mg/dL), Mean (SD)]; Within group, Mean (SD): before, after; Hydrogenated: 104.7 (19.5), 107.1 (21.2), P=0.141; Ghee: 114.8 (27.2), 113.7 (23.9), P=0.126; Unhydrogenated: 105.9 (22.6), 104.3 (24.4), P=0.387; Blended: 108.6 (23.8), 107.1 (23.5), P=0.451; Margarine: 105.8 (28.7), 101.8 (25.4), P=0.109; Between group, β (95% CI): post-study change; Hydrogenated: REF; Ghee: −2.5 (−6.6, 1.7), P=NS; [underlined: HDL (mg/dL), Mean (SD)]; Within group, Mean (SD): before, after; Hydrogenated: 43.3 (7.5), 44.1 (7.0), P=0.233; Ghee: 44.0 (5.6), 45.3 (7.6), P=0.244; Unhydrogenated: 45.3 (6.9), 44.3 (6.8), P=0.324; Blended: 47.2 (6. 8), 47.4 (7.3), P=0.438; Margarine: 45.3 (6.8), 46.0 (6.0), P=0.345; Between group, β (95% CI): post-study change; Hydrogenated: REF; Ghee: 0.6 (−1.1, 2.3), P=NS; [underlined: TG (mg/dL), Mean (SD)]; Within group, Mean (SD): before, after; Hydrogenated: 134.1 (52.8), 137.5 (51.8), P=0.124; Ghee: 125.0 (52.0), 122.6 (49.3), P=0.512; Unhydrogenated: 127.4 (42.1), 122.8 (41.6), P< 0.001; Blended: 109.5 (26.1), 95.5 (24.9), P=0.010; Margarine: 114.9 (33.7), 108.2 (31.1), P< 0.001; Between group, β (95% CI): post-study change; Hydrogenated: REF; Ghee: −6.3 (−10.7, −2.0), P<0.01 | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Very little information provided on each condition; Insufficient information on randomization and allocation procedures; No power calculation; Funding: NR
Palomäki, 2010^21^; RCT-crossover, Finland Analytic N = 37; Adequately powered: NR; Study aims: To assess whether a dietary intake of cold-pressed turnip rapeseed oil has beneficial effects on serum lipids, oxidized LDL and arterial elasticity compared to an intake of butter among men with metabolic syndrome; Participant characteristics:; - Age: Mean NR; 30-65 y (inclusion criteria); - Female: 0%; - Race and/or ethnicity: NR; - SEP: NR; - BMI 31.0 (5.0) kg/m2; - Health Status: 100% MetS; Excluded women and those that did no fulfill NCEP Adult Treatment Panel criteria for MetS | Intervention and Comparators:; - Butter: 37.5 g/d of butter with maximal water content of 16% and 61.7% SFA, 33.7% MUFA, 2.9% PUFA; participants were asked to spread the butter on bread during the butter period (25g/d SFA; total fat NR); - Rapeseed oil: 35 mL/d of cold-pressed turnip rapeseed oil with 4.5% SFA, 60.6% MUFA, 35.0% PUFA; participants were asked to drink the oil and eat their bread without spread during the oil period (1.5 ml/d SFA; total fat NR); Intervention duration: 6-8 wk (8wk washout); Other Group Differences: Participants were asked to maintain their normal dietary habits and physical activity without major variations.; Compliance: No; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood collection and blood pressure at the end of both dietary periods | [underlined: LDL (mmol/L), Mean (SD)]; Butter: 3.35 (0.21); Rapeseed oil: 3.00 (0.18); P<0.001; [underlined: HDL (mmol/L), Mean (SD)]; Butter: 1.15 (0.04); Rapeseed oil: 1.15 (0.04); P=NS; [underlined: TG (mmol/L), Mean (SD)]; Butter: 2.72 (0.30); Rapeseed oil: 2.56 (0.38); P=NS; [underlined: SBP, mmHg, Mean (SD)]; Butter: 138.5 (2.2); Rapeseed oil: 138.5 (2.6); P=NS; [underlined: DBP, mmHg, Mean (SD)]; Butter: 81.8 (1.4); Rapeseed oil: 81.3 (1.6); P=NS | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: No information on randomization or allocation procedures; No power calculation; Participants were not blinded; Funding: Medical Research Fund of Kanta-Häme Central Hospital (Ministry of Health and Social Welfare in Finland); Häme Regional Fund (Finnish Cultural Foundation); Kankaisten Öljykasvit Ltd; Hilkka and Väinö Kiltti Foundation
Holmberg, 2009^39^; PCS, Sweden; Analytic N = 1752; Participant characteristics:; - Age: 50.2 y (6.0), Range: 39-62 y; - Female: 0%; - Race and/or ethnicity: NR; - SEP: 57% farmer; 43% non-farmer; - BMI 26.4 (3.2) kg/m2, Range: 18.3-44.4; - Health Status: Generally healthy; LDL: 3.8 (1.0) mmol/L, Range: 0.5-7.6; SBP: 134 (17), Range: 96-219; Included farmers (≥25hr/wk farming) and age-, sex-, and residential areamatched non-farmers; excluded previous hospitalization for CHD | Exposure and Comparators:; Low-fat dairy: low-fat milk, no butter, seldom/never cream;; Low-fat milk;; MUFA/PUFA: low-fat margarine or no fat (spread on sandwiches); All categorical (Yes/No if primary fat level of dairy consumed); High-fat dairy: full-fat milk and/or butter and/or cream, categorical (Yes/No if primary fat level of dairy consumed);; Dairy: High-fat milk;; Dairy: Butter (specifically as spread on sandwiches); Exposure assessment method: FFQ at baseline; Baseline intake of study foods: NR; Outcome(s): Death or hospitalization due to CHD; Outcome assessment methods and timing: National Cause of Death Register (CHD mortality) and Hospital Patient Register (CHD morbidity); assessed across; 12 y at 12 y follow-up | [underlined: CVD mortality over 12 y, by baseline intake, OR (95% CI)]; High-fat dairy (n=1373) = REF; Low-fat dairy (n=346): 1.80 (1.22, 2.66); [underlined: CVD mortality over 12 y, by baseline intake, OR (95% CI)]; High-fat milk (n=838) = REF; Low-fat milk (n=908): 1.43 (1.00, 2.04); [underlined: CVD mortality over 12y, by baseline intake, OR (95% CI)]; Butter (n=845) = REF; Low-fat margarine or no fat (n=894): 1.10 (0.78, 1.56) | Key confounders accounted for: Sex (♀ only); Key confounders NOT accounted for: Age, race and/or ethnicity, socioeconomic position, physical activity, anthropometry, smoking, alcohol, diet quality, total energy intake; Other covariates accounted for: LDL, SBP; Limitations: Exposure measured at baseline only; no preregistered data analysis plan; Funding: AFA Insurance, LRF Research Foundation, The Swedish Council for Working Life and Social Research, Kronoberg County Council
Pancheco, 2022^48^; PCS, United States, NHS, HPFS; Analytic N = 110,487; Participant characteristics:; - Age: 52.87 (Men); 52.48 (Women); - Female: 62%; - Race and/or ethnicity: 97% White; - SEP: 100% nurses or health professionals; - BMI: 25.5 kg/m2 (men); 25.3 kg/m2 (women); - Health Status: Generally healthy; LDL greater than 130 mg/dl; mean 167 (28) mg/dl; - HDL: 48(11) mg/dl; - TG: 148 (64) mg/dl; - TC: 245 (33) mg/dl; - VLDL: 29 (12) mg/dl; Excluded participants with a baseline history of heart disease, stroke, or cancer. Excluded participants with missing information on avocado intake and implausible energy intake. | Exposure and Comparators:; - Avocado, 1/2 serving substitution; - Cheese, regular and low-fat or light (cottage or ricotta, cream, and all other cheeses including hard); - Butter; Exposure assessment method: FFQ assessed every 4 y; Baseline intake of study foods: NR; Outcome(s): Total CVD: composite of fatal CHD and nonfatal myocardial infarction and fatal and nonfatal stroke Total CHD: Fatal CHD and nonfatal myocardial infarction Total stroke: Fatal and nonfatal ischemic, hemorrhagic, and unknown subtypes of stroke; Outcome assessment methods and timing: Non-fatal: Self-reported + medical records reviewed by physicians; Fatal: National Death Index, family members response in questionnaire, report from participant’s professional organizations at 30 y (Median f/u for men: 13.3; women: 14.2 y) follow-up | [underlined: CVD, HR (95% CI)]; Replacing butter with avocado: 0.78 (0.63, 0.96); Replacing cheese with avocado: 0.87 (0.77, 0.98); [underlined: CHD, HR (95% CI)]; Replacing butter with avocado: 0.69 (0.53, 0.90); Replacing cheese with avocado: 0.75 (0.65, 0.87); [underlined: Stroke, HR (95% CI)]; Replacing butter with avocado: 0.89 (0.63, 1.25); Replacing cheese with avocado: 1.07 (0.90, 1.28) | Key confounders accounted for: Sex,; Age,; Race/ethnicity,; SEP,; Physical activity,; Anthropometry,; Smoking,; Alcohol,; Diet quality,; Total energy; Key confounders NOT accounted for: None; Other covariates accounted for: Family history of diabetes, MI, baseline diabetes; baseline hypertension or antihypertensive medication use; baseline hypercholesterolemia or cholesterol-lowering medication use; multivitamin use; aspirin use; red and processed meat, fruits and vegetables (excluding avocado), nuts, soda (caloric and low or noncaloric), whole grains, eggs, tortilla (whole and chips), breads, cheese intakes; trans-fat, and mutually adjusted for other types of fat-containing foods; Limitations: % fat in the dairy foods is not specific. Participants are well-educated and mostly White, so the findings may not be generalizable. Multiple comparisons were not adjusted/accounted for.; Funding: NIH, Harvard Chan Yerby Fellowship
Guasch-Ferré, 2022^36^; PCS, United States, NHS, HPFS; Analytic N = 92,383 (60,582 in NHS; 31,801 in HPFS); Participant characteristics:; - Age: ~56 y; 44-69 y (NHS), 44-79 y (HPFS); - Female: 0.66; - Race and/or ethnicity: 97% White; - SEP: 100% nurses or health professionals; - Mean BMI: ~25.5; - Health Status: Generally healthy; 19% HTN; 27% hypercholesterolemia; Excluded those with history of CVD or cancer at baseline; those with missing data for olive oil; those with implausible energy intake | Exposure and Comparators: Continuous (10 g/d substitution); - Dairy, butter (added to foods and used for frying, sauteing, and baking) and dairy fat (source, % fat not specified); - Olive oil: used as salad dressing, added to food or bread, or used for baking and frying at home; 1 tbsp = 13.5 g; Exposure assessment method: Validated FFQ every 4 years; Baseline intake of study foods: NR; Outcome(s): CVD mortality; Outcome assessment methods and timing: Physician review of medical records, medical reports, autopsy reports, or death certificates at 28 y follow-up | [underlined: CVD-mortality per 10 g/d substitution, Pooled HR (95% CI)]; Olive oil for dairy fat: 0.92 (0.87, 0.97); Olive oil for butter: 0.93 (0.87, 0.99) | Key confounders accounted for: Sex, age, race and/or ethnicity, socioecononomic position (all nurses or health professionals, marital status, living alone), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, whole grains, red meat, nuts, soda, trans fat), TEI; Key confounders NOT accounted for: None; Other covariates accounted for: Family history of DM; family Hx MI; family Hx Cx; multivitamin use; aspirin use; menopausal status and hormone use (NHS); other types of fat (margarine, mayonnaise, other vegetable oils); butter (for dairy fat analyses); dairy fat (for butter analyses); Limitations: No preregistered data analysis plan; Funding: NIH
Hosseinabadi, 2022^18^; RCT-crossover, Iran; Analytic N = 30; Adequately powered: Yes; Study aims: To evaluate the cardiovascular health-related effects of consuming ghee in the usual diet; Participant characteristics:; - Age: 37.5 (9.5) y; 20-60 y; - Female: NR; - Race and/or ethnicity: NR (100% Iranian); - SEP: NR; - BMI 25.9 (4.4) kg/m2; - Health Status: Generally healthy; Baseline values (mmol/L); - LDL: 2.80 (0.70); - HDL: 1.11 (0.24); - TG: 1.57 (1.12); Excluded those <20 or >60y; menopausal females; T2D, CHD, abnormal liver function test (ALT and AST > 45 U/L ), abnormal kidney function test (creatinine > 1.4 mg/dL), on lipid lowering medication, pregnancy and breast feeding, female on oral contraceptive unless they have no intention to change during the study | Intervention and Comparators:; - Olive oil, refined (19% SFA, 60% MUFA, 21% PUFA); - Ghee, clarified butter sourced from commercial manufacturer (62.5% SFA; 30.8% MUFA; 5.1% PUFA) as 15% of total daily energy intake; Intervention duration: 4 wk each (2wk washout); Other Group Differences: Participants were delivered oil/fat every 2wk and instructed to prepare lunch and dinner using the studied oil/fat so that more than 80% of the daily oil/fat used in meal prepared were from the study oil/fat. NS difference between groups for energy intake, CHO, PRO, total fat, or fiber.; Compliance: Yes, ≥80% based on selfreported consumption; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood collection and blood pressure measurements at baseline and after each 4wk period | [underlined: LDL (mmol/L), Mean difference (95% CI)] Ghee: 0.10 (−0.09, 0.30); Olive oil: −0.18 (−0.40, 0.03); Between group: −0.29 (−0.63, 0.05), P=0.092; [underlined: HDL (mmol/L), Mean difference (95% CI)]; Ghee: −0.05 (−0.12, 0.03); Olive oil: −0.04 (−0.09, 0.01); Between group: 0.01 (−0.10, 0.11), P=0.924; [underlined: TG (mmol/L), Mean difference (95% CI)]; Ghee: 0.44 (−0.10, 0.97); Olive oil: −0.07 (−0.35, 0.21); Between group: −0.50 (−1.20, 0.19), P=0.150; [underlined: SBP (mmHg), Mean difference (95% CI)] Ghee: 0.23 (−4.00, 4.47); Olive oil: −1.73 (−5.27, 1.81); Between group: −1.97 (−7.97, 3.98), P=0.504; [underlined: DBP (mmHg), Mean difference (95% CI)]; Ghee: −4.13 (−7.42, −0.84); Olive oil: −4.23 (−6.61, −1.85); Between group: −0.10 (−4.21, 4.01), P=0.961 | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations:; Funding: National Nutrition and Food Technology Research Institute (Shahid Beheshti University of Medical Science, Iran)
Zhang, 2021^51^; PCS, United States, NIH-AARP Diet and Health Study Analytic N = 521,120; Participant characteristics:; - Age: 62.8 y; 50-71 y; - Female: 41%; - Race and/or ethnicity: 92% White, 4% Black, 2% Hispanic, 2% Asian; - SEP: 39% college or postgraduate; household income ~$50K/yr (in 1999); 68% married; - BMI ~ 26 kg/m2; - Health Status: Generally healthy; 14% heart disease; 9% T2D; Excluded those who were proxy responders, had duplicate records, decided to withdraw, moved or died before entry, and had a null personyears of follow-up or extreme total energy intake (<800 or >4200 kcal/day for men and <600 or >3500 kcal/day for women) | Exposure and Comparators: Continuous (1 tbsp/d substitution); - Butter: consumption and during cooking (1 tbsp ~14g); - Margarine: consumption and during cooking (1 tbsp ~14g); - Vegetable oils: corn, canola, olive; consumption and during cooking (1 tbsp ~8g); Exposure assessment method: FFQ at baseline; Baseline intake of study foods: 42% butter consumers; median intake in highest tertile of consumers 13.7g per 2000 kcal/d; Outcome(s): CVD mortality; Outcome assessment methods and timing: Annual linkage to the Social Security Administration Death Master File and confirmed by follow-up searches of the National Death Index; ICD9 and ICD 10 for death cause classification; 99% complete follow-up rate at 16 y follow-up | [underlined: CVD mortality by 1 tbsp/d substitution, HR (95% CI)]; Butter for margarine: 1.01 (0.98, 1.03), P=0.49; Margarine for butter: 0.99 (0.97, 1.02), P=0.49; Corn oil for butter: 0.96 (0.92, 1.00), P=0.055; Canola oil for butter: 0.93 (0.89, 0.97), P=0.002; Olive oil for butter: 0.93 (0.89, 0.97), P<0.001 | Key confounders accounted for: Sex, age, race and/or ethnicity, socioeconomic position (marital status, education, household income), physical activity, anthropometry (BMI), smoking, alcohol, diet quality (HEI-2015), total energy intake; Key confounders NOT accounted for: None; Other covariates accounted for: perceived health condition, history of heart disease, stroke, diabetes and cancer at baseline; total cooking oil intake; Limitations: Exposure measured at baseline only; No preregistered data analysis plan; Funding: Zhejiang Provincial Natural Science Foundation of China; National Natural Science Foundation of China; Intramural Research Program of the NIH National Cancer Institute
Guasch-Ferré, 2020^37^; PCS, United States, NHS, HPFS; Analytic N = 93,041 (61,181 in NHS; 31,797 in HPFS); Participant characteristics:; - Age: ~65 y; 26-69 y (NHS) and 44-79 y (HPFS); - Female: 66%; - Race and/or ethnicity: 97% White; - SEP: All nurses or health professionals; - BMI ~26 kg/m2; - Health Status: Generally healthy; 42% HTN; 51% hypercholesterolemia; Excluded those with cancer, heart disease, or stroke; missing data for olive oil; daily energy intake <600 or >3500 kcal for women, or <800 or >4200 kcal for men | Exposure and Comparators: Continuous (5 g/d substitution); - Olive oil: used as salad dressing, added to food or bread, or used for baking and frying at home; 1 tbsp = 13.5 g; - Butter: added to foods and used for frying, sauteing, and baking; - Dairy fat: details NR; Exposure assessment method: Validated FFQ at baseline and every 4 years; Baseline intake of study foods: NR; Outcome(s): CVD, CHD, Stroke; Outcome assessment methods and timing: Physician review of medical records, medical reports, autopsy reports, or death certificates at 24 y follow-up | [underlined: CVD per 5 g/d substitution, Pooled HR (95% CI)]; Olive oil for butter: 0.95 (0.91, 1.00), P=0.06; Olive oil for dairy fat: 0.95 (0.92, 0.98), P<0.001; [underlined: CHD per 5 g/d substitution, Pooled HR (95% CI)]; Olive oil for butter: 0.94 (0.89, 1.01); Olive oil for dairy fat: 0.93 (0.89, 0.97); [underlined: Stroke per 5 g/d substitution, Pooled HR (95% CI)]; Olive oil for butter: 0.96 (0.89, 1.04); Olive oil for dairy fat: 0.98 (0.93, 1.04); Data NR for NHS and HPFS separately (figure only) | Key confounders accounted for: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, whole grains, red meat, nuts, soda, trans fat), TEI; Key confounders NOT accounted for: Socioeconomic position; Other covariates accounted for: Family history of diabetes, myocardial infarction, cancer; T2DM; HTN or antihypertensive medication use; hypercholesterolemia or cholesterol-lowering medication use; multivitamin or aspirin use; postmenopausal status and menopausal hormone use (women); other types of fat (e.g., margarine, mayonnaise, vegetable oils); Limitations: No preregistered data analysis plan; Funding: NIH
Judd, 1998^12^; RCT-crossover, United States; Analytic N = 46; Adequately powered: No; Study aims: To compare margarine with butter to determine effects on plasma lipids, lipoprotein profiles, vitamin E, and lipid hydroperoxide concentrations.; Participant characteristics:; - Age: 46.8 (1.44) y, 28-65 y; - Female: 50%; - Race and/or ethnicity: NR; - SEP: NR; - BMI 25.3 (0.44) kg/m2; - Health Status: Healthy, Normolipidemic; Excluded those with HTN, hyperlipidemia, diabetes, PVD, gout, liver or kidney disease, or endocrine disorders; <85% or >120% of sexspecific ideal BMI based on life insurance reference tables; taking lipidlowering drugs, blood pressure medications, or dietary supplements; eating habits that were inconsistent with study protocol (e.g., vegetarian, low-fat); HDL ≤65 mmol/L for men and ≤0.91 mmol/L for women; TG >3.39 mmol/L; those with LDL <25% or >75% were selected to participate | Intervention and Comparators:; - Butter: obtained from commercial creamery (53% SFA, 31% MUFA, 5% PUFA); - Trans-margarine: tub-type margarine produced to align trans 18:1 isomers of typical U.S. margarines based on partially hydrodgenated soybean oil (16% SFA, 48% MUFA, 27% PUFA); - PUFA-margarine: tub-type margarine produced by blending liquid sunflower oil with completely hydrogenated soybean and canola oils (21% SFA, 20.5% MUFA, 49% PUFA); Intervention duration: 5 wk each (no washout); Other Group Differences: Participants were fed the same items and the same proportions of each item relative to total dietary energy (i.e., relative amounts of all nutrients such as fiber were constant for all participants, aside from nutrients provided by intervention); Compliance: Yes, “excellent” based on direct observation of meal consumption, weight maintenance, and daily questionnaires; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood collection at baseline and after each 5wk period | [underlined: LDL (mmol/L) after 5wk, Mean (SEE)]; Butter: 3.44 (0.09); Trans-margarine: 3.27 (0.09); PUFA-margarine: 3.21 (0.09); Butter vs. trans-margarine: P<0.05; Butter vs. PUFA-margarine: P<0.05; [underlined: HDL (mmol/L) after 5wk, Mean (SEE)]; Butter: 1.27 (0.04); Trans-margarine: 1.24 (0.04); PUFA-margarine: 1.24 (0.04); Butter vs. trans-margarine: NS; Butter vs. PUFA-margarine: NS; [underlined: TG (mmol/L) after 5wk, Mean (SEE)]; Butter: 0.98 (0.05); Trans-margarine: 0.99 (0.05); PUFA-margarine: 0.92 (0.05); Butter vs. trans-margarine: NS; Butter vs. PUFA-margarine: NS | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: No information on randomization or allocation procedures; No power calculation; No preregistered data analysis plan; Funding: USDA-ARS; Unilever Research Laboratory
Brassard, 2017^6^; RCT-crossover, Canada; Analytic N = 92; Adequately powered: Yes; Study aims: To assess the impact of consuming equal amounts of SFA from cheese, butter vs. MUFA, PUFA and CHO on cardiometabolic risk factors; Participant characteristics:; - Age: 39.2 y; 18-65 y; - Female: 53%; - Race and/or ethnicity: 72% White; 8% Black; 8% Hispanic; 11% Asian; 2% Other; - SEP: NR; - BMI: 30.79 kg/m2; - Health Status: 100% Abdominal obesity; All participants with HDL below the age- and sex-specific 75th percentiles (≤1.34 and ≤1.53 mmol/L for men and women, respectively); Excluded individuals with high HDLcholesterol concentrations, a history of CVD, type 2 diabetes, or monogenic dyslipidemia; the use of medications for hypertension, hyperlipidemia, or glycemic control; uncontrolled endocrine disorder such as hypothyroidism or hyperthyroidism; smoking; a Framingham-calculated CAD risk score >20%; any food allergies or aversion to foods that were included in the menu; particular nutritional habits such as vegetarianism; and women with menstrual irregularities including those who were experiencing perimenopause. Participants not allowed to use anti-inflammatory drugs. Included participants with waist circumference ≥94 and ≥80 cm for men and women, respectively, and have HDL-cholesterol concentrations below the age- and sex-specific 75th percentiles (≤1.34 and ≤1.53 mmol/L for men and women, respectively) | Intervention and Comparators:; - MUFA: diet rich in MUFA (5.8% SFA; 19.6% MUFA; 4.8% PUFA; 51.9% CHO); - PUFA: diet rich in PUFA (5.8% SFA; 12.6% MUFA; 11.5% PUFA; 51.9% CHO); - CHO: high CHO, low- fat (5.8% SFA; 12.6% MUFA; 4.8% PUFA; 58.9% CHO); - Cheese: 90 g/2500 kcal (12.6% SFA; 12.5% MUFA; 4.8% PUFA; 51.9% CHO); - Butter: 48.9 g/2500 kcal (12.4% SFA; 12.3% MUFA; 4.8% PUFA; 52% CHO); Intervention duration: 4 wk each (≥24d washout period); Other Group Differences: SFA in butter and cheese was matched.; Diets were identical in terms of energy, protein, cholesterol, sodium and fiber contents; calcium and potassium were higher in the cheese condition than the other 4.; Compliance: Yes; Participants filled checklist. Excluded participants from the treatment phases where compliance was; <80%; Compliance: 98.7% ± 2.4% after the exclusion of non-compliant subjects; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood measured twice on consecutive days at the end of each dietary phase. Mean of the two measurements was used | [underlined: LDL (mmol/L), Mean (SD)]; Cheese: 3.19 (0.81); Butter: 3.30 (0.84); MUFA: 3.03 (0.78); PUFA: 2.84 (0.69); Cheese vs. MUFA: P<0.05; Butter vs. MUFA: P<0.05; Cheese vs. PUFA: P<0.05; Butter vs. PUFA: P<0.05; [underlined: HDL (mmol/L), Mean (SD)]; Cheese: 1.10 (0.19); Butter: 1.11 (0.21); MUFA: 1.10 (0.19); PUFA: 1.10 (0.20); Cheese vs. MUFA; Cheese vs. PUFA; Butter vs.; PUFA; Butter vs. MUFA: P>0.05; [underlined: TG (mmol/L), Mean (SD)]; Cheese: 1.43 (0.70); Butter: 1.36 (0.73); MUFA: 1.38 (0.67); PUFA: 1.30 (0.62); Cheese vs. PUFA: P<0.05; Cheese vs. MUFA; Butter vs. PUFA; Butter vs.; MUFA: P>0.05; Results were also provided from ITT with similar findings; [underlined: SBP (mmHg), Mean (SD)]; Cheese: 109.9 (13.4); Butter: 109.0 (12.4); MUFA: 111.4 (12.9); PUFA: 109.9 (13.0); P (between group)>0.05; [underlined: DBP (mmHg), Mean (SD)]; Cheese: 70.0 (10.4); Butter: 68.9 (9.8); MUFA: 68.7 (9.8); PUFA: 68.8 (11.3); P (between group)>0.05; Results were also provided from ITT with similar findings; [underlined: LDL (mmol/L), Mean (SD)]; Cheese: 3.19 (0.81); Butter: 3.30 (0.84); CHO: 3.11 (0.79); Cheese vs. CHO: P<0.05; Butter vs. CHO: P<0.05; [underlined: HDL (mmol/L), Mean (SD)]; Cheese: 1.10 (0.19); Butter: 1.11 (0.21); CHO: 1.06 (0.19); Cheese vs. CHO: P<0.05; Butter vs. CHO: P<0.05; [underlined: TG (mmol/L), Mean (SD)]; Cheese: 1.43 (0.70); Butter: 1.36 (0.73); CHO: 1.46 (0.71); Butter vs. CHO: P<0.05; Cheese vs. CHO: P>0.05; Results were also provided from ITT with similar findings; [underlined: SBP (mmHg), Mean (SD)]; Cheese: 109.9 (13.4); Butter: 109.0 (12.4) CHO: 109.8 (12.6); P (between group)>0.05; [underlined: DBP (mmHg), Mean (SD)]; Cheese: 70.0 (10.4); Butter: 68.9 (9.8); CHO: 69.9 (10.0); P (between group)>0.05; Results were also provided from ITT with similar findings; [underlined: LDL (mmol/L), Mean (SD)]; Cheese: 3.19 (0.81); Butter: 3.30 (0.84); P<0.05; [underlined: HDL (mmol/L), Mean (SD)]; Cheese: 1.10 (0.19); Butter: 1.11 (0.21); P>0.05; [underlined: TG (mmol/L), Mean (SD)]; Cheese: 1.43 (0.70); Butter: 1.36 (0.73); P<0.05; Results were also provided from ITT with similar findings; [underlined: SBP (mmHg), Mean (SD)]; Cheese: 109.9 (13.4); Butter: 109.0 (12.4); P>0.05; [underlined: DBP (mmHg), Mean (SD)]; Cheese: 70.0 (10.4); Butter: 68.9 (9.8); P>0.05; Results were also provided from ITT with similar findings | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: High drop-out rates; Funding: Fondation du Centre Hospitalier Universitaire de Québec – Université Laval; Green Fund of the Government of Québec

a Abbreviations: β: beta; %tile: percentile; BMI: body mass index; BP: blood pressure; CAD: Coronary Artery Disease; CE: cholesterol esters; CHO: carbohydrate; CI: confidence interval; CVD: Cardiovascular disease; CHD: Coronary heart disease; d: day; DBP: diastolic blood pressure; FFQ: food frequency questionnaire; g: grams; HDL: high-density lipoprotein; HTN: Hypertension; hx: history; LDL: low-density lipoprotein; mg: milligram; ml: milliliter; mmol: millimoles; mo: months; MI: Myocardial Infarction; MUFA: monounsaturated fatty acids; NA: not applicable; NIH: National Institutes of Health; NR: not reported; NS: non-significant; PCS: prospective cohort study; PRO: Protein; PUFA: polyunsaturated fatty acids; RCT: Randomized controlled trial; REF: reference; SBP: systolic blood pressure; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SFA: Saturated fatty acids; SSB: sugar-sweetened beverages; TG: triglycerides; wk: week; wks: weeks; y: year

Table 40 Risk of bias for randomized controlled trials examining butter compared to food sources of unsaturated fatty acids^a^

Article | Randomization | Period and carryover effects | Deviations from intended interventions (effect of assignment) | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Mohammadifard, 2013^27^ | SOME CONCERNS | NOT APPLICABLE | NOT APPLICABLE | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | HIGH
Denke, 2000^1^ | HIGH | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | HIGH
Lichtenstein, 1999^15^ | SOME CONCERNS | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Cox, 1998^8^ | HIGH | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | HIGH
Chisholm, 1996^7^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Wood, 1993^24^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Engel, 2015^10^ | LOW | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Morillas-Ruiz, 2014^19^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Palomaki, 2010^21^ | SOME CONCERNS | LOW | NOT APPLICABLE | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS
Hosseinabadi, 2022^18^ | LOW | LOW | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW
Judd, 1998^12^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Brassard, 2017^6^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898. )

Table 41 Risk of bias for observational studies examining butter compared to food sources of unsaturated fatty acids^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Laursen, 2018^43^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Liu, 2017^46^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Holmberg, 2009^39^ | VERY HIGH | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | VERY HIGH
Pancheco, 2022^48^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Guasch-Ferré, 2022^36^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Zhang, 2021^51^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Guasch-Ferré, 2020^37^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Laursen, 2019^44^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Kvist, 2020^42^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 42 Evidence examining the relationship between substituting one form of dairy with another form^a^

Study and Participant Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Methodological Considerations
Nestel, 2005^20^; RCT-crossover, Australia; Analytic N = 19 Adequately powered: Yes; Study aims: To determine whether dairy fat in cheese raises LDL cholesterol as much as in butter; Participant characteristics:; - Age: 56.3 (7.8) y; - Female: 26%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 27.7 (4.6); - Health Status: Overweight; 100% Hypercholesterolemia (mild); LDL-C of >3.6 mmol/l but <6mmol/l at the initial screen; Were not on drugs; Excluded participants with diabetes or other metabolic disturbances | Intervention and Comparators:; - Butter (40 g/d); - Cheese (120 g/d for 40 g/d of dairy fat); Intervention duration: 4 wk; Other Group Differences: NS between groups: total energy, total fat, SFA, PUFA, MUFA, Carbohydrate, Protein, Cholesterol; Compliance: NR; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood lipids after 4 wk trial | [underlined: LDL, Median (25, 75%)]; Butter: 3.9 (3.5, 4.1); Cheese: 3.7 (3.3, 3.9); P=0.07; Only among those with elevated LDL (>4 mmol/L); Cheese: 3.9 (0.4); Butter: 4.4 (0.4); P=0.014; [underlined: HDL, Mean (SD)]; Butter: 1.6 (0.4); Cheese: 1.5 (0.4); P=NS; [underlined: TG, Median (25, 75%)]; Butter: 1.1 (0.9, 1.4); Cheese: 1.5 (0.8, 1.6); P=NS; [underlined: BP]; Data NR, P=NS | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Participants were not blinded. Unclear if the researchers were blinded; Funding: Murray Goulburn Dairy Company; Dairy Australia
Laursen, 2018^43^; PCS, Denmark, Danish Diet, Cancer, and Health; Analytic N = 55,211; Participant characteristics:; - Age: 56 y; 51-63 y; - Female: 52%; - Race and/or ethnicity: NR; - SEP: 24% with elementary and secondary education ≥10y; - BMI 25.5 kg/m2; - Health Status: 16% HTN; 7% Hypercholesterolemia; Excluded those <50y and >64y not born in Denmark, existing cancer diagnosis at baseline, stroke before baseline, missing data | Exposure and Comparators: Continuous (1 svg/d substitution); - Low-fat milk for: whole-fat milk, buttermilk; Whole milk for buttermilk; - Semi-skimmed fermented milk for: whole-fat fermented milk, low-fat milk, whole-fat milk, buttermilk; - Whole-fat fermented milk for: low-fat milk, whole-fat milk, buttermilk; - Cheese for: low-fat milk, whole-fat milk, buttermilk, semi-skimmed fermented milk, whole-fat fermented milk, butter; Substitution of dairy foods:; - Low-fat milk (skimmed milk, 0.3% fat; semi-skimmed milk, 1.5% fat); 1 svg = 200 g; - Whole-fat milk (3.5% fat); 1 svg = 200 g; - Buttermilk (0.5% fat); 1 svg = 200 g; - Semi-skimmed fermented milk (yogurt-type products with 1.5% fat, with or without added fruit); 1 svg = 200 g; - Whole-fat fermented milk (yogurt-type products with 3.5% fat, with or without added fruit); 1 svg = 200 g; - Cheese (semi-hard cheese, soft matured cheese, blue cheese, cottage cheese and cream cheese); 1 svg = 20 g; - Butter (details NR); 1 svg = 6 g; Exposure assessment method: FFQ at baseline; Baseline intake of study foods: Median (80% central range) in svg/d; - Low-fat milk: 0.21 (0.03-2.56); - Whole-fat milk: 0.05 (0.01-0.52); - Buttermilk: 0.03 (0.00-0.44); - Semi-skimmed fermented milk: 0.02 (0.00-0.80); - Whole-fat fermented milk: 0.06 (0.01-1.00); - Cheese: 1.43 (0.50-3.44); - Butter: 1.55 (0.00-5.07); - Fresh red meat: 0.52 (0.27-0.94); - Processed red meat: 1.64 (0.53-3.96); Outcome(s): Stroke (total, ischemic, intracerebral hemorrhagic, subarachnoid hemorrhagic, or unspecified type of stroke).; Ischemic stroke further classified according to TOAST-criteria as large artery atherosclerosis, lacunar (small-vessel occlusion), cardioembolism, and stroke of other or unknown etiology.; Outcome assessment methods and timing: Danish National Patient Registry at 13.4 y follow-up | [underlined: Total stroke by 1 svg/d substitution, HR (95% CI)]; Low-fat milk for whole-fat milk: 0.97 (0.91, 1.04); Semi-skimmed fermented milk for whole-fat fermented milk: 1.08 (0.91, 1.28); [underlined: Ischemic stroke by 1 svg/d substitution, HR (95% CI)]; Low-fat milk for whole-fat milk: 0.97 (0.90, 1.04); Semi-skimmed fermented milk for whole-fat fermented milk: 1.14 (0.94, 1.38); [underlined: Intracerebral hemorrhagic stroke by 1 svg/d]; substitution, HR (95% CI); Low-fat milk for whole-fat milk: 1.06 (0.87, 1.29); Semi-skimmed fermented milk for whole-fat fermented milk: 1.11 (0.68, 1.80); [underlined: Subarachnoid hemorrhagic stroke by 1 svg/d]; substitution, HR (95% CI); Low-fat milk for whole-fat milk: 0.85 (0.67, 1.09); Semi-skimmed fermented milk for whole-fat fermented milk: 0.66 (0.34, 1.29); Data also provided by ischemic stroke sub-type (large artery atherosclerosis, lacunar, cardioembolism); By 1 svg/d substitution, HR (95% CI); Low-fat milk for buttermilk; Total stroke: 0.97 (0.88, 1.06); Ischemic stroke: 0.97 (0.87, 1.07); Intracerebral hemorrhagic stroke: 0.94 (0.74, 1.20); Subarachnoid hemorrhagic stroke: 1.01 (0.68, 1.51); Whole-fat milk for buttermilk; Total stroke: 1.00 (0.90, 1.11); Ischemic stroke: 1.00 (0.89, 1.12); Intracerebral hemorrhagic stroke: 0.89 (0.66, 1.20); Subarachnoid hemorrhagic stroke: 1.19 (0.77, 1.83); Semi-skimmed fermented milk for low-fat milk; Total stroke: 0.99 (0.87, 1.13); Ischemic stroke: 1.00 (0.87, 1.15); Intracerebral hemorrhagic stroke: 0.97 (0.67, 1.39); Subarachnoid hemorrhagic stroke: 1.00 (0.57, 1.74); Semi-skimmed fermented milk for whole-fat milk; Total stroke: 0.96 (0.84, 1.10); Ischemic stroke: 0.97 (0.83, 1.12); Intracerebral hemorrhagic stroke: 1.02 (0.69, 1.51); Subarachnoid hemorrhagic stroke: 0.85 (0.48, 1.49); Semi-skimmed fermented milk for buttermilk; Total stroke: 0.96 (0.82, 1.12); Ischemic stroke: 0.97 (0.82, 1.15); Intracerebral hemorrhagic stroke: 0.91 (0.59, 1.39); Subarachnoid hemorrhagic stroke: 1.01 (0.52, 1.97); Whole-fat fermented milk for low-fat milk; Total stroke: 0.91 (0.80, 1.04); Ischemic stroke: 0.88 (0.76, 1.01); Intracerebral hemorrhagic stroke: 0.87 (0.60, 1.26); Subarachnoid hemorrhagic stroke: 1.51 (0.97, 2.37); Whole-fat fermented milk for whole-fat milk; Total stroke: 0.89 (0.77, 1.02); Ischemic stroke: 0.85 (0.73, 0.99); Intracerebral hemorrhagic stroke: 0.92 (0.61, 1.39); Subarachnoid hemorrhagic stroke: 1.29 (0.80, 2.09); Whole-fat fermented milk for buttermilk; Total stroke: 0.89 (0.76, 1.04); Ischemic stroke: 0.85 (0.71, 1.01); Intracerebral hemorrhagic stroke: 0.82 (0.53, 1.27); Subarachnoid hemorrhagic stroke: 1.53 (0.85, 2.77); Cheese for low-fat milk; Total stroke: 0.96 (0.92, 1.01); Ischemic stroke: 0.97 (0.92, 1.02); Intracerebral hemorrhagic stroke: 0.91 (0.80, 1.03); Subarachnoid hemorrhagic stroke: 1.02 (0.84, 1.25); Cheese for whole-fat milk; Total stroke: 0.93 (0.87, 1.00); Ischemic stroke: 0.94 (0.87, 1.01); Intracerebral hemorrhagic stroke: 0.96 (0.78, 1.18); Subarachnoid hemorrhagic stroke: 0.87 (0.68, 1.12); Cheese for buttermilk; Total stroke: 0.93 (0.85, 1.02); Ischemic stroke: 0.94 (0.84, 1.04); Intracerebral hemorrhagic stroke: 0.85 (0.66, 1.10); Subarachnoid hemorrhagic stroke: 1.03 (0.69, 1.55); Cheese for semi-skimmed fermented milk; Total stroke: 0.97 (0.85, 1.10); Ischemic stroke: 0.97 (0.84, 1.12); Intracerebral hemorrhagic stroke: 0.94 (0.65, 1.35); Subarachnoid hemorrhagic stroke: 1.02 (0.59, 1.78); Cheese for whole-fat fermented milk; Total stroke: 1.05 (0.92, 1.20); Ischemic stroke: 1.11 (0.96, 1.28); Intracerebral hemorrhagic stroke: 1.04 (0.72, 1.50); Subarachnoid hemorrhagic stroke: 0.67 (0.43, 1.06); Cheese for butter; Total stroke: 0.96 (0.92, 1.00); Ischemic stroke: 0.96 (0.92, 1.00); Intracerebral hemorrhagic stroke: 0.98 (0.87, 1.10); Subarachnoid hemorrhagic stroke: 0.97 (0.82, 1.16); Data also provided by ischemic stroke sub-type (large artery atherosclerosis, lacunar, cardioembolism) | Key confounders accounted for: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol intake, diet quality (intake of fruit, vegetables, red meat, processed meat, and fish), total energy intake; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: HTN, hypercholesterolemia, diabetes, and previous myocardial infarction; Limitations: Exposure measured at baseline only; No preregistered data analysis plan; Funding: Danish Council for Strategic Research (Innovation Fund Denmark)
Rosqvist, 2015^33^; RCT-parallel, Sweden, MFGM study; Analytic N = 57; Adequately powered: Yes - study conducted power calculations and reported that 23 participants are needed per group. However, one group had 26 participants while the other had only 20 participants; Study aims: To investigate whether the effects of milk fat on plasma lipids and cardiometabolic risk markers are modulated by the milk fat globule membrane content; Participant characteristics:; - Age: MFGM group: 58.5 y; Control: 60.5 y; 20 to 70y; - Female: 60%; - Race and/or ethnicity: NR; - SEP: NR; - BMI 28; - Health Status: 100% Overweight; Excluded participants with CVD, diabetes, or liver disease; the use of lipid-lowering drugs, omega-3 supplements, or extreme diets; an intolerance to gluten or milk protein; pregnancy or lactation; regular heavy exercise (>3 h/wk); or abnormal clinical chemistry | Intervention and Comparators:; - Butter oil control: 40 g fat per day from 1 dL fat-free milk (0.1% fat) and 1 scone (baked with wheat flour, water, butter oil with 98.7% fat, sodium chloride, baking powder, and milk protein isolate); - Whipping cream: 40 g fat per day from 1 dL whipping cream (40% fat, enclosed with milk fat globule membrane), 1 dL fat-free milk (0.1% fat), and 1 scone (baked with wheat flour, water, sodium chloride, and baking powder); Intervention duration: 8 wk; Other Group Differences: Isocaloric; Diets were matched for total energy, fat, SFA, CHO, protein, and calcium; MFGM diet phospholipid 19.8 mg, control diet phospholipid 1.3 mg; Compliance: Yes, based on daily checklists and weekly dialogues; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood collection at baseline and 8wk | [underlined: LDL (mmol/L)]; Within group: absolute change at 8wk, Mean (SD); Butter oil control: 0.36 (0.50); Whipping cream: 0.04 (0.36); Between group: difference in change, Mean (95% CI); 0.31 (0.04, 0.58); P=0.024 (per protocol); P=0.034 (ITT); [underlined: HDL (mmol/L)]; Within group: absolute change at 8wk, Mean (SD); Butter oil control: 0.06 (0.16); Whipping cream: 0.10 (0.22); Between group: difference in change, Mean (95% CI); −0.04 (−0.015, 0.07); P=0.74 (per protocol); [underlined: TG (mmol/L)]; Within group: absolute change at 8wk, Mean (SD); Butter oil control: 0.07 (0.47); Whipping cream: −0.012 (0.25); Between group: difference in change, Mean (95% CI); 0.08 (−0.16, 0.32); P=0.49 (per protocol) | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: No information on randomization or allocation procedures; Isocaloric study; Study may not have been sufficiently powered; Results may not be transferrable to butter; Funding: Swedish Medical Research Council; Arla Foods; Skånemejerier AB; Semper AB; Dairy Sweden
Schlienger, 2014^32^; RCT-parallel, France; Analytic N = 156; Adequately powered: Yes; Study aims: To assess the impact of saturated fatty acid from cheese and full-fat yogurt on lipid parameters and blood pressure; Participant characteristics:; - Age: 49.1 (11.3) y; 18 to 65 y; - Female: 47%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 19 to 30 kg/m2; Camembert: 25.2 (3.1); yogurt: 25.5 (3.3); - Health Status: 100% hypercholesterolemia; Overweight; Moderate hypercholesterolemia: 4.13< LDL-cholesterol< 5.70mmol/l, and TAG>2.5 g/l; No medication against hypertension or hypercholesterolemia during intervention and 2 mo before the study; Excluded participants with diabetes, CVD, or other metabolic disturbances other than moderate hypercholesterolemia, any serious illness that could influence the results or treatment with drugs that affect plasma lipid values, with lactose intolerance, milk protein allergies, or who disliked the products used in the study or refused to follow dietary recommendations, pregnant and breast-feeding women or women wishing to get pregnant in the 3 months following inclusion | Intervention and Comparators:; - Yogurt, full-fat, 250 g/d (2*125); SFA: 5.4 g; - Camembert cheese, 2*30g/day; SFA: 8 g; Run-in period: During the 21-d run-in period, participants were given 2 x 125 g pot of full-fat yogurt; Intervention duration: 5 wk; Other Group Differences: Differences:; - Dietary frequency score significantly different between yogurt (7.1(3.8)) and cheese (5.0(4.1)) groups;; - SFA significantly different between yogurt (2.1 (1.7)) and cheese (3.6(2.4)) groups; - Caloric intake was slightly higher in yogurt (186 kcal) vs. Camembert (160.8 kcal) and so was CHO (yogurt (12 g) & Camembert (traces)); No difference in: MUFA, PUFA (ω3 and ω6), ω3/ω6, fruits & veg; Participants were asked not to modify their living habits including physical activity level, habitual daily alcohol intake, smoking habits; provided dietary recommendations, i.e., low-cholesterol diet; also requested not to consume other cheeses or fermented dairy products at lunch and dinner but free to consume non-fermented dairy products at breakfast.; Compliance: Yes; 95.5%, no difference between groups; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood samples at participants selection, the beginning and during the run-in period, at the beginning, during and at the end of the experimental period for lipids; supine position for blood pressure | [underlined: HDL (mmol/l), Mean (SD)]; During intervention; Yogurt: 1.44 (0.33); Cheese: 1.47 (0.38); End of intervention; Yogurt: 1.47 (0.37); Cheese: 1.50 (0.39); P value: NS; [underlined: LDL (mmol/l), Mean (SD)]; During intervention; Yogurt: 4.19 (0.54); Cheese: 4.17 (0.62); End of intervention; Yogurt: 4.18 (0.54); Cheese: 4.24 (0.61); P value: NS; [underlined: TG (mmol/l), Mean (SD)]; During intervention; Yogurt: 1.32 (0.56); Cheese: 1.45 (0.85); End of intervention; Yogurt: 1.35 (0.61); Cheese: 1.40 (0.62); P value: NS; [underlined: SBP (mmHg), Mean (SD)]; End of intervention; Yogurt: 120.2 (13.4); Cheese: 119.5 (13.1); P value: NS; [underlined: DBP (mmHg), Mean (SD)]; End of intervention; Yogurt: 75.5 (8.9); Cheese: 73.4 (10.1); P value=0.06 | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Study may not have been sufficiently powered. Based on power calculations, 160 participants were required; 159 participated and 156 completed the study; Funding: President, Lactalis, France
Hjerpsted, 2011^11^; RCT-crossover, Denmark; Analytic N = 49; Adequately powered: No; Study aims: To compare the effect of diets of equal fat content rich in either hard cheese or butter or a habitual diet on blood pressure and fasting serum blood lipids.; Participant characteristics:; - Age: 55.5 (12.4) y; 22 to 69 y; - Female: 43%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 25.3 (3.3); - Health Status: Five subjects using antihypertensive medication; Excluded participants with current or previous CVD, diabetes or other severe chronic disease, BMI>32kg/m2, use of lipid-lowering agents, and known or suspected abuse of alcohol, drugs, or medication. | Intervention and Comparators:; - Butter, 47 g/day for medium level energy; - Cheese (Samso, 27g fat/100g), 143 g/day for medium level energy (low vs medium vs high energy level: ≤ 9.8 MJ, 9.8-12.5 MJ, ≥ 12.5 MJ); 2-wk run-in period of habitual diet; washout period of ≥2 wk on habitual diet. Subjects could choose to consume none, 1.5, 3, 4.5, or 6 cL/d of milk and consume the same amout throughout the study.; Intervention duration: 6 wk; Other Group Differences: Similar fat composition between cheese and butter; differ in calcium; Compliance: Yes; Outcome(s): TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood sample in duplicate on consecutive days, after the run-in period, 3 wk and 6 wk of the intervention | [underlined: TG (mmol/l), Mean (SEM)]; Run-in: 1.06 (1.06); Cheese: 1.15 (1.06); Butter: 1.17 (1.06); P-value: NS; [underlined: SBP (mmHg), Mean (SEM)]; Run-in: 127 (1.02); Cheese: 125 (1.02); Butter: 127 (1.02); P-value: NS; [underlined: DBP (mmHg), Mean (SEM)]; Run-in: 79.4 (1.04); Cheese: 78.7 (1.05); Butter: 79.8 (1.05); P-value: NS | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Percentage of energy as fat in the diet during the cheese period was lower than that during the butter period; Funding: Danish Dairy Board Denmark and the Dairy Research Institute, Rosemont, IL
Laursen, 2019^44^; PCS, The Netherlands, EPIC-NL (comprised of 2 cohorts: Prospect & MORGEN); Analytic N = 36,886; Participant characteristics:; - Age: 51 y; 31-63 y; - Female: 75%; - Race and/or ethnicity: NR; - SEP: 58% low educational attainment (primary up to intermediate vocational); - BMI 25.1 kg/m2; - Health Status: 37% HTN; 8.5% Hypercholesterolemia; Excluded participants that did not permit register linkage; previous stroke; poor diet reporters (top and bottom 0.5% of the ratio of energy intake to estimated basal metabolic rate); missing data on exposures or covariates | Exposure and Comparators: Continuous (1 svg/d substitution; also conducted sensitivity analyses with isocaloric 100kcal/d substitutions); - Low-fat yogurt for: whole-fat yogurt, low-fat milk, whole-fat milk, buttermilk, cheese, butter; - Whole-fat yogurt for: low-fat milk, whole-fat milk, buttermilk, cheese, butter; - Low-fat milk for: whole-fat milk, buttermilk, cheese, butter; - Whole milk for: buttermilk, cheese, butter; - Buttermilk for: cheese, butter; - Cheese for butter; Substitution of dairy foods:; - Low-fat milk (skimmed and semi-skimmed milk, <2% fat); 1 svg = 200 g; - Whole-fat milk (whole-fat, raw and powdered milk, ≥3% fat); 1 svg = 200 g; - Buttermilk (details NR); 1 svg = 200 g; - Low-fat yogurt products (skimmed and semi-skimmed regular and drink yogurt, <2% fat, curd); 1 svg = 200 g; - Whole-fat yogurt products (regular and drink yogurt, ≥3% fat); 1 svg = 200 g; - Cheese (details NR); 1 svg = 20 g; - Butter (details NR); 1 svg = 6 g; Exposure assessment method: FFQ at baseline; Baseline intake of study foods: Median (80% central range) in svg/d; Low-fat milk: 0.46 (0.05-1.71); Whole-fat milk: 0.15 (0.01-0.59); Buttermilk: 0.00 (0.00-1.00); Low-fat yogurt: 0.15 (0.01-0.68); Whole-fat yogurt: 0.05 (0.00-0.28); Cheese: 1.50 (0.36-3.38); Butter: 0.46 (0.12-2.06); Fresh red meat: 0.41 (0.11-0.70); Processed red meat: 1.37 (0.20-4.07); Outcome(s): Stroke (total, ischaemic, hemorrhagic); Outcome assessment methods and timing: Standardized register for hospital discharge diagnoses; 15y median follow up, participants followed until the date of an incident stroke, death from another cause, loss to follow-up or end of study at Median: 15 y follow-up | Total stroke, by 1 svg/d substitution, HR (95% CI); Low-fat yogurt for whole-fat yogurt: 1.32 (0.73, 2.36); Low-fat milk for whole-fat milk: 0.99 (0.78, 1.25); Ischemic stroke, by 1 svg/d substitution, HR (95% CI); Low-fat yogurt for whole-fat yogurt: 2.27 (0.99, 5.22); Low-fat milk for whole-fat milk: 0.92 (0.68, 1.23); Hemorrhagic stroke, by 1 svg/d substitution, HR (95% CI); Low-fat yogurt for whole-fat yogurt: 0.70 (0.25, 1.93); Low-fat milk for whole-fat milk: 1.38 (0.82, 2.33); Also provided data by 100kcal substitutions between dairy products; [underlined: Total stroke by 1 svg/d substitution, HR (95% CI)]; Low-fat yogurt for low-fat milk: 0.91 (0.75, 1.11); Low-fat yogurt for whole-fat milk: 0.90 (0.70, 1.16); Low-fat yogurt for buttermilk: 0.93 (0.76, 1.14); Low-fat yogurt for cheese: 0.91 (0.76, 1.10); Low-fat yogurt for butter: 0.91 (0.76, 1.10); Whole-fat yogurt for low-fat milk: 0.69 (0.40, 1.20); Whole-fat yogurt for whole-fat milk: 0.68 (0.39, 1.22); Whole-fat yogurt for buttermilk: 0.70 (0.41, 1.22); Whole-fat yogurt for cheese: 0.69 (0.40, 1.19); Whole-fat yogurt for butter: 0.69 (0.40, 1.19); Low-fat milk for buttermilk: 1.02 (0.90, 1.16); Low-fat milk for cheese: 1.00 (0.90, 1.12); Low-fat milk for butter: 1.00 (0.90, 1.11); Whole-fat milk for buttermilk: 1.03 (0.84, 1.26); Whole-fat milk for cheese: 1.01 (0.84, 1.23); Whole-fat milk for butter: 1.01 (0.83, 1.24); Buttermilk for cheese: 0.99 (0.88, 1.10); Buttermilk for butter: 0.98 (0.88, 1.10); Cheese for butter: 1.00 (0.92, 1.08); [underlined: Ischaemic stroke by 1 svg/d substitution, HR (95% CI)]; Low-fat yogurt for low-fat milk: 0.87 (0.67, 1.15); Low-fat yogurt for whole-fat milk: 0.80 (0.58, 1.11); Low-fat yogurt for buttermilk: 0.89 (0.68, 1.18); Low-fat yogurt for cheese: 0.88 (0.69, 1.14); Low-fat yogurt for butter: 0.88 (0.69, 1.13); Whole-fat yogurt for low-fat milk: 0.38 (0.18, 0.85); Whole-fat yogurt for whole-fat milk: 0.35 (0.16, 0.79); Whole-fat yogurt for buttermilk: 0.39 (0.18, 0.87); Whole-fat yogurt for cheese: 0.39 (0.18, 0.85); Whole-fat yogurt for butter: 0.39 (0.18, 0.85); Low-fat milk for buttermilk: 1.02 (0.86, 1.21); Low-fat milk for cheese: 1.01 (0.88, 1.17); Low-fat milk for butter: 1.01 (0.88, 1.16); Whole-fat milk for buttermilk: 1.12 (0.86, 1.44); Whole-fat milk for cheese: 1.11 (0.87, 1.40); Whole-fat milk for butter: 1.10 (0.86, 1.42); Buttermilk for cheese: 0.99 (0.86, 1.15); Buttermilk for butter: 0.99 (0.85, 1.15); Cheese for butter: 1.00 (0.89, 1.11); [underlined: Hemorrhagic stroke by 1 svg/d substitution, HR (95% CI)]; Low-fat yogurt for low-fat milk: 0.90 (0.63, 1.30); Low-fat yogurt for whole-fat milk: 1.25 (0.74, 2.11); Low-fat yogurt for buttermilk: 1.02 (0.70, 1.47); Low-fat yogurt for cheese: 0.95 (0.68, 1.32); Low-fat yogurt for butter: 0.88 (0.64, 1.22); Whole-fat yogurt for low-fat milk: 1.30 (0.50, 3.37); Whole-fat yogurt for whole-fat milk: 1.79 (0.63, 5.08); Whole-fat yogurt for buttermilk: 1.46 (0.56, 3.82); Whole-fat yogurt for cheese: 1.36 (0.53, 3.47); Whole-fat yogurt for butter: 1.27 (0.50, 3.24); Low-fat milk for buttermilk: 1.12 (0.88, 1.44); Low-fat milk for cheese: 1.05 (0.85, 1.28); Low-fat milk for butter: 0.98 (0.81, 1.19); Whole-fat milk for buttermilk: 0.81 (0.51, 1.29); Whole-fat milk for cheese: 0.76 (0.49, 1.17); Whole-fat milk for butter: 0.71 (0.45, 1.11); Buttermilk for cheese: 0.93 (0.76, 1.15); Buttermilk for butter: 0.87 (0.71, 1.07); Cheese for butter: 0.93 (0.81, 1.07); Also provided data by 100kcal substitutions between dairy products | Key confounders accounted for: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol intake, diet quality (Dutch Health Diet Index 2015), total energy intake; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: HTN; hypercholesterolemia; DM; myocardial infarction; cohort; Limitations: Exposure measured at baseline only; No preregistered data analysis plan; Funding: European Commission; Dutch Ministry of Health, Welfare, and Sports; Netherlands Organisation for Health Research and Development; World Cancer Research Fund
Brassard, 2017^6^; RCT-crossover, Canada; Analytic N = 92 Adequately powered: Yes; Study aims: To assess the impact of consuming equal amounts of SFA from cheese, butter vs. MUFA, PUFA and CHO on cardiometabolic risk factors; Participant characteristics:; - Age: 39.2 y; 18-65 y; - Female: 53%; - Race and/or ethnicity: 72% White; 8% Black; 8% Hispanic; 11% Asian; 2% Other; - SEP: NR; - BMI: 30.79 kg/m2; - Health Status: 100% Abdominal obesity; All participants with HDL below the age- and sex-specific 75th percentiles (≤1.34 and ≤1.53 mmol/L for men and women, respectively); Excluded individuals with high HDL-cholesterol concentrations, a history of CVD, type 2 diabetes, or monogenic dyslipidemia; the use of medications for hypertension, hyperlipidemia, or glycemic control; uncontrolled endocrine disorder such as hypothyroidism or hyperthyroidism; smoking; a Framingham-calculated CAD risk score >20%; any food allergies or aversion to foods that were included in the menu; particular nutritional habits such as vegetarianism; and women with menstrual irregularities including those who were experiencing perimenopause. Participants not allowed to use anti-inflammatory drugs.; Included participants with waist circumference ≥94 and ≥80 cm for men and women, respectively, and have HDL-cholesterol concentrations below the age- and sex-specific 75th percentiles (≤1.34 and ≤1.53 mmol/L for men and women, respectively) | Intervention and Comparators:; - MUFA: diet rich in MUFA (5.8% SFA; 19.6% MUFA; 4.8% PUFA; 51.9% CHO); - PUFA: diet rich in PUFA (5.8% SFA; 12.6% MUFA; 11.5% PUFA; 51.9% CHO); - CHO: high CHO, low-fat (5.8% SFA; 12.6% MUFA; 4.8% PUFA; 58.9% CHO); - Cheese: 90 g/2500 kcal (12.6% SFA; 12.5% MUFA; 4.8% PUFA; 51.9% CHO); - Butter: 48.9 g/2500 kcal (12.4% SFA; 12.3% MUFA; 4.8% PUFA; 52% CHO); Intervention duration: 4 wk each (≥24d washout period); Other Group Differences: SFA in butter and cheese was matched.; Diets were identical in terms of energy, protein, cholesterol, sodium and fiber contents; calcium and potassium were higher in the cheese condition than the other 4.; Compliance: Yes; Participants filled checklist. Excluded participants from the treatment phases where compliance was <80%; Compliance: 98.7% ± 2.4% after the exclusion of non-compliant subjects; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood measured twice on consecutive days at the end of each dietary phase. Mean of the two measurements was used | [underlined: LDL (mmol/L), Mean (SD)]; Cheese: 3.19 (0.81); Butter: 3.30 (0.84); MUFA: 3.03 (0.78); PUFA: 2.84 (0.69); Cheese vs. MUFA: P<0.05; Butter vs. MUFA: P<0.05; Cheese vs. PUFA: P<0.05; Butter vs. PUFA: P<0.05; [underlined: HDL (mmol/L), Mean (SD)]; Cheese: 1.10 (0.19); Butter: 1.11 (0.21); MUFA: 1.10 (0.19); PUFA: 1.10 (0.20); Cheese vs. MUFA; Cheese vs. PUFA; Butter vs. PUFA; Butter vs. MUFA: P>0.05; [underlined: TG (mmol/L), Mean (SD)]; Cheese: 1.43 (0.70); Butter: 1.36 (0.73); MUFA: 1.38 (0.67); PUFA: 1.30 (0.62); Cheese vs. PUFA: P<0.05; Cheese vs. MUFA; Butter vs. PUFA; Butter vs. MUFA: P>0.05; Results were also provided from ITT with similar findings; [underlined: SBP (mmHg), Mean (SD)]; Cheese: 109.9 (13.4); Butter: 109.0 (12.4); MUFA: 111.4 (12.9); PUFA: 109.9 (13.0); P (between group)>0.05; [underlined: DBP (mmHg), Mean (SD)]; Cheese: 70.0 (10.4); Butter: 68.9 (9.8); MUFA: 68.7 (9.8); PUFA: 68.8 (11.3); P (between group)>0.05; Results were also provided from ITT with similar findings; [underlined: LDL (mmol/L), Mean (SD)]; Cheese: 3.19 (0.81); Butter: 3.30 (0.84); CHO: 3.11 (0.79); Cheese vs. CHO: P<0.05; Butter vs. CHO: P<0.05; [underlined: HDL (mmol/L), Mean (SD)]; Cheese: 1.10 (0.19); Butter: 1.11 (0.21); CHO: 1.06 (0.19); Cheese vs. CHO: P<0.05; Butter vs. CHO: P<0.05; [underlined: TG (mmol/L), Mean (SD)]; Cheese: 1.43 (0.70); Butter: 1.36 (0.73); CHO: 1.46 (0.71); Butter vs. CHO: P<0.05; Cheese vs. CHO: P>0.05; Results were also provided from ITT with similar findings; [underlined: SBP (mmHg), Mean (SD)]; Cheese: 109.9 (13.4); Butter: 109.0 (12.4); CHO: 109.8 (12.6); P (between group)>0.05; [underlined: DBP (mmHg), Mean (SD)]; Cheese: 70.0 (10.4); Butter: 68.9 (9.8); CHO: 69.9 (10.0); P (between group)>0.05; Results were also provided from ITT with similar findings; [underlined: LDL (mmol/L), Mean (SD)]; Cheese: 3.19 (0.81); Butter: 3.30 (0.84); P<0.05; [underlined: HDL (mmol/L), Mean (SD)]; Cheese: 1.10 (0.19); Butter: 1.11 (0.21); P>0.05; [underlined: TG (mmol/L), Mean (SD)]; Cheese: 1.43 (0.70); Butter: 1.36 (0.73); P<0.05; Results were also provided from ITT with similar findings; [underlined: SBP (mmHg), Mean (SD)]; Cheese: 109.9 (13.4); Butter: 109.0 (12.4); P>0.05; [underlined: DBP (mmHg), Mean (SD)]; Cheese: 70.0 (10.4); Butter: 68.9 (9.8); P>0.05; Results were also provided from ITT with similar findings | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: High drop-out rates; Funding: Fondation du Centre Hospitalier Universitaire de Québec – Université Laval; Green Fund of the Government of Québec
Laursen, 2022^45^; PCS, Denmark, Danish Diet, Cancer, and Health; Analytic N = 55775; Participant characteristics:; - Age: 56.2 y; 51-63 y; - Female: 52%; - Race and/or ethnicity: NR; - SEP: 21% educational attainment >10y; BMI 25.5 kg/m2; - Health Status: 16% HTN; 7.5% Hypercholesterolemia; Excluded those <50y and >64y not born in Denmark, existing cancer diagnosis at baseline, missing data on any exposure or covariate | Exposure and Comparators: Continuous (1 svg/d substitution); - Low-fat milk (skimmed milk, 0.3% fat; semi-skimmed milk, 1.5% fat); 1 svg = 200 g; - Whole milk (whole-fat milk, 3.5% fat); 1 svg = 200 g; - Buttermilk (0.5% fat); 1 svg = 200 g; - Whole-fat yogurt (whole-fat yogurt products with 3·5% fat, with and without added fruit); 1 svg = 200 g; - Low-fat yogurt (semi-skimmed yogurt products with 1·5% fat, with and without added fruit); 1 svg = 200 g; - Cheese (semi-hard cheese, soft matured cheese, blue cheese, cottage cheese and cream cheese); 1 svg = 20 g; Substitution of dairy foods:; - Low-fat yogurt for: whole-fat yogurt, low-fat milk, whole-fat milk, buttermilk, cheese, butter; - Whole-fat yogurt for: low-fat milk, whole-fat milk, buttermilk, cheese, butter; - Low-fat milk for: whole-fat milk, buttermilk, cheese, butter; - Whole milk for: buttermilk, cheese, butter; - Buttermilk for: cheese, butter; - Cheese for butter; Exposure assessment method: FFQ at baseline; Baseline intake of study foods: Median (80% central range) in g/d; - Low-fat milk: 42 (6-513); - Whole-fat milk: 10 (3-104); - Buttermilk: 6 (0-88); - Low-fat yogurt: 3 (0-160); - Whole-fat yogurt: 13 (1-200); - Cheese: 29 (10-69); - Butter: 9 (0-30); - Red meat: 78 (41-141); - Processed meat: 25 (8-60); Outcome(s): CVD mortality; Outcome assessment methods and timing: Danish Causes of Death register at 19 y follow-up | [underlined: CVD mortality by 1 svg/d substitution, HR (95% CI)]; Men (n=26,614; cases=1491); Low-fat milk for whole-fat milk: 0.97 (0.91, 1.04); Low-fat yogurt for whole-fat yogurt: 1.10 (0.88, 1.38); Women (n=29,161; cases=668); Low-fat milk for whole-fat milk: 0.95 (0.83, 1.08); Low-fat yogurt for whole-fat yogurt: 0.93 (0.71, 1.21); Also conducted sensitivity analyses excluding participants with MI or stroke at baseline, poor energy reporters (top and bottom 0.5% of the ratio of reported energy intake to EER), and non-consumers of any dairy subgroup, as well as analyses restricting to non-smokers; [underlined: CVD mortality by 1 svg/d substitution, HR (95% CI)]; Men (n=26,614; cases=1491); Low-fat milk for buttermilk: 1.11 (0.96, 1.27); Low-fat milk for low-fat yogurt: 0.95 (0.80, 1.12); Low-fat milk for whole-fat yogurt: 1.04 (0.89, 1.22); Low-fat milk for cheese: 1.07 (1.02, 1.13); Whole-fat milk for buttermilk: 1.14 (0.98, 1.32); Whole-fat milk for low-fat yogurt: 0.98 (0.82, 1.15); Whole-fat milk for whole-fat yogurt: 1.07 (0.90, 1.27); Whole-fat milk for cheese: 1.10 (1.02, 1.19); Buttermilk for low-fat yogurt: 0.86 (0.69, 1.06); Buttermilk for whole-fat yogurt: 0.94 (0.76, 1.17); Buttermilk for cheese: 0.97 (0.84, 1.11); Low-fat yogurt for cheese: 1.13 (0.96, 1.33); Whole-fat yogurt for cheese: 1.03 (0.87, 1.21); Women (n=29,161; cases=668); Low-fat milk for buttermilk: 0.96 (0.84, 1.10); Low-fat milk for low-fat yogurt: 1.01 (0.83, 1.23); Low-fat milk for whole-fat yogurt: 0.94 (0.76, 1.16); Low-fat milk for cheese: 1.06 (0.98, 1.15); Whole-fat milk for buttermilk: 1.01 (0.85, 1.20); Whole-fat milk for low-fat yogurt: 1.07 (0.86, 1.32); Whole-fat milk for whole-fat yogurt: 0.99 (0.78, 1.26); Whole-fat milk for cheese: 1.12 (0.98, 1.28); Buttermilk for low-fat yogurt: 1.06 (0.84, 1.33); Buttermilk for whole-fat yogurt: 0.98 (0.77, 1.26); Buttermilk for cheese: 1.11 (0.96, 1.28); Low-fat yogurt for cheese: 1.05 (0.86, 1.27); Whole-fat yogurt for cheese: 1.13 (0.91, 1.39); Also conducted sensitivity analyses excluding participants with MI or stroke at baseline, poor energy reporters (top and bottom 0.5% of the ratio of reported energy intake to EER), and non-consumers of any dairy subgroup, as well as analyses restricting to non-smokers | Key confounders accounted for: Sex, age, socioeconomic position (educational attainment), physical activity, anthropometry, smoking, alcohol intake, diet quality (intake of fruit, vegetables, red meat, processed meat, and fish), total energy intake; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: Date of inclusion (as stratum variable); HTN; hypercholesterolemia; Limitations: Exposure measured at baseline only; No preregistered data analysis plan; Funding: Danish Cancer Society
Kvist, 2020^42^; PCS, Denmark, Danish Diet, Cancer, and Health; Analytic N = 54,903; Participant characteristics:; - Age: 56 y; 50-64 y; - Female: 53%; - Race and/or ethnicity: NR (100% Danish); - SEP: 33% education length <8y; - BMI 25.5 kg/m2; - Health Status: Generally healthy, without history of cancer or MI; Excluded those with Hx cancer; Hx MI; incomplete data on exposure or covariates | Exposure and Comparators: Continuous (1 svg/d substitution); - Whole-fat milk with: low-fat milk, whole-fat yogurt, low-fat yogurt, cheese; - Low-fat milk with: low-fat yogurt, whole-fat yogurt, cheese; - Buttermilk with: low-fat milk, whole-fat milk, low-fat yogurt, whole-fat yogurt, cheese; - Whole-fat yogurt with: low-fat yogurt, cheese; - Low-fat yogurt with cheese; - Butter with cheese; Substitution of dairy foods:; - Whole-fat milk (3.5% fat); 1 svg = 200 g; - Low-fat milk (skimmed milk, 0.3% fat; semi-skimmed milk, 1.5% fat); 1 svg = 200 g; - Buttermilk (0.5% fat); 1 svg = 200 g; - Whole-fat yogurt (3.5% fat); 1 svg = 200 g; - Low-fat yogurt (1.5% fat); 1 svg = 200 g; - Cheese (fat NR; semi-hard cheese, soft matured cheese, blue cheese, cottage cheese and cream cheese); 1 svg = 20 g; - Butter (details NR); 1 svg = 6 g; Exposure assessment method: FFQ at baseline; Baseline intake of study foods: Median (80% central range) in svg/d; cohorts, cases:; Red meat: 0.52 (0.27-0.93), 0.59 (0.31-1.04); Processed meat: 1.64 (0.53-3.96), 2.09 (0.67-4.66); Whole-fat milk: 0.05 (0.02-0.52), 0.05 (0.15-1.02); Low-fat milk: 0.21 (0.03-2.56), 0.22 (0.03-2.58); Buttermilk: 0.03 (0-0.44), 0.03 (0-0.38); Whole-fat yogurt: 0.06 (0.01-1), 0.05 (0.01-0.82); Low-fat yogurt: 0.02 (0-0.8), 0 (0-0.51); Cheese: 1.43 (0.50-3.44), 1.33 (0.45-3.26); Butter: 1.56 (0-5.08), 1.97 (0-5.28); Outcome(s): Myocardial infarction; Outcome assessment methods and timing: Danish National Patient Register and Danish Register of Causes of Death at 15.9 y follow-up | [underlined: Myocardial infarction by 1 svg/d substitution, HR (95% CI)]; Low-fat milk for whole-fat milk: 0.97 (0.92, 1.02); Low-fat yogurt for whole-fat yogurt: 0.99 (0.85, 1.15); Men; Low-fat milk for whole-fat milk: 0.97 (0.92, 1.03); Low-fat yogurt for whole-fat yogurt: 0.97 (0.80, 1.19); Women; Low-fat milk for whole-fat milk: 0.94 (0.84, 1.05); Low-fat yogurt for whole-fat yogurt:1.02 (0.84, 1.26); [underlined: Myocardial Infarction, HR (95% CI), per 1 svg]; Replacement of whole-fat milk with:; - whole-fat yogurt: 0.89 (0.79, 1.00); - low-fat yogurt: 0.88 (0.78, 0.99); - cheese: 0.93 (0.88, 0.98); Replacement of low-fat milk with:; - low-fat yogurt: 0.91 (0.81, 1.01); - whole-fat yogurt: 0.92 (0.82, 1.02); - cheese: 0.96 (0.92, 0.99); Replacement of buttermilk with:; - low-fat milk: 1.01 (0.93, 1.10); - whole-fat milk: 1.05 (0.95, 1.14); - low-fat yogurt: 0.92 (0.80, 1.06); - whole-fat yogurt: 0.93 (0.81, 1.07); - cheese: 0.97 (0.89, 1.05); Replacement of whole-fat yogurt with cheese: 1.04 (0.93, 1.17); Replacement of low-fat yogurt with cheese: 1.05 (0.94, 1.19); Replacement of butter with cheese: 0.98 (0.95, 1.02); [underlined: Myocardial Infarction, HR (95% CI), per 1 svg, men only]; Replacement of whole-fat milk with:; - whole-fat yogurt: 0.91 (0.78, 1.04); - low-fat yogurt: 0.89 (0.76, 1.04); - cheese: 0.95 (0.89, 1.01); Replacement of low-fat milk with:; - low-fat yogurt: 0.91 (0.78, 1.06); - whole-fat yogurt: 0.94 (0.82, 1.07); - cheese: 0.98 (0.94, 1.02); Replacement of buttermilk with:; - low-fat milk: 1.03 (0.92, 1.15); - whole-fat milk: 1.06 (0.94, 1.20); - low-fat yogurt: 0.94 (0.78, 1.13); - whole-fat yogurt: 0.96 (0.81, 1.15); - cheese: 1.01 (0.90, 1.13); Replacement of whole-fat yogurt with cheese: 1.05 (0.91, 1.20); Replacement of low-fat yogurt with cheese: 1.08 (0.92, 1.25); Replacement of butter with cheese: 0.99 (0.94, 1.03); [underlined: Myocardial Infarction, HR (95% CI), per 1 svg, women only]; Replacement of whole-fat milk with:; - whole-fat yogurt: 0.83 (0.66, 1.03); - low-fat yogurt: 0.83 (0.69, 1.02); - cheese: 0.85 (0.76, 0.96); Replacement of low-fat milk with:; - low-fat yogurt: 0.88 (0.74, 1.06); - whole-fat yogurt: 0.87 (0.71, 1.05); - cheese: 0.90 (0.83, 0.96); Replacement of buttermilk with:; - low-fat milk: 1.00 (0.88, 1.15); - whole-fat milk: 1.06 (0.90, 1.24); - low-fat yogurt: 0.89 (0.71, 1.10); - whole-fat yogurt: 0.87 (0.69, 1.10); - cheese: 0.90 (0.78, 1.03); Replacement of whole-fat yogurt with cheese: 1.03 (0.84, 1.26); Replacement of low-fat yogurt with cheese: 1.01 (0.84, 1.22); Replacement of butter with cheese: 0.96 (0.90, 1.02) | Key confounders accounted for: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality, total energy intake; Key confounders NOT accounted for: Race and/or ethnicity (100% Danish); Other covariates accounted for: date of entry into study, red meat intake, processed meat intake, fish intake, vegetable intake, fruit intake, HTN, hypercholesterolemia, DM; Limitations: Exposure measured at baseline only; Funding: None received
Phosat, 2022^30^; RCT-parallel, Thailand; Analytic N = 51 (Cow’s milk, N=12; Goat milk, N=14; Goat milk with curcumin, N=13; Goat milk with coffee, N=12); Adequately powered: NR; Study aims: To investigate the effects of goat’s milk powder on the health of lactose intolerant middle-aged adults.; Participant characteristics:; - Age: 50 y (median); 45.0-54.0 (IQR); 40-60y (eligible age range); - Female: 92%; - Race and/or ethnicity: NR but likely majority Asian; - SEP: NR; - BMI ~23 kg/m2; - Health Status: Primarily healthy, lactose intolerant; Included lactose intolerant adults ages 40-60y; Excluded those with chronic disease (e.g., DM, CKD, Cancer), those with infection or inflammation in previous 6 months, taking medication or nutritional supplements, smoking, or regularly drinking alcohol; Excluded pregnant or lactating individuals | Intervention and Comparators:; - Goat’s milk: 40.0 g goat’s milk powder (contains 31.9% fat, 28.0% protein, 32.3% lactose);; - Cow’s milk: 46.5 g lactose-free cow’s milk powder (contains 30.0% fat, 16.0% protein, lactose-free); Other comparators:; - Goat’s milk + curcumin: 40.0 g goat’s milk powder and 0.025 g extracted curcumin powder (contains 31.9% fat, 28% protein, 32.3% lactose);; - Goat’s milk + coffee: 40.0 g goat’s milk powder and 0.025 g coffee powder (contains 31.9% fat, 28.0% protein, 32.3% lactose); Intervention duration: 5 wk; Other Group Differences: Isocaloric (~211 kcal/day); Compliance: Yes, 85% completed intervention; participants took photos of dietary items prior to and after intake but data NR; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood collection and blood pressure measured at baseline and 5wk | [underlined: LDL (mmol/L), Median (IQR)]; Within group: baseline, 5wk; Goat’s milk: 3.4 (2.4-3.9), 3.2 (2.5-3.6), P=0.600; Goat’s milk + curcumin: 3.1 (2.7-3.5), 3.1 (2.5-4.0), P=0.789; Goat’s milk + coffee: 3.5 (3.0-3.7), 3.7 (3.3-4.2), P=0.114; Cow’s milk: 3.0 (2.7-4.1), 2.9 (2.5-3.7), P=0.091; Between group: difference at 5wk P=0.200; [underlined: HDL (mmol/L), Median (IQR)]; Within group: baseline, 5wk; Goat’s milk: 1.6 (1.4-2.0), 1.5 (1.4-1.8), P=0.002; Goat’s milk + curcumin: 1.9 (1.6-2.0), 1.7 (1.4-2.0), P=1.52; Goat’s milk + coffee: 1.7 (1.6-2.1), 1.8 (1.5-1.9), P=0.075; Cow’s milk: 2.2 (1.5-2.7), 1.9 (1.5-2.4), P=0.006; Between group: difference at 5wk P=0.199; Cow’s milk vs all comparisons: P=NS; [underlined: TG (mmol/L), Median (IQR)]; Within group: baseline, 5wk; Goat’s milk: 1.0 (0.7-1.2), 1.0 (0.9-1.2), P=0.925; Goat’s milk + curcumin: 0.9 (0.6-1.0), 0.9 (0.6-1.1), P=0.953; Goat’s milk + coffee: 1.0 (0.9-1.2), 1.1 (1.0-1.4), P=0.066; Cow’s milk: 0.8 (0.8-1.2), 0.9 (0.8-1.1), P=0.824; Between group: difference at 5wk P=0.034; Cow’s milk vs Goat’s milk + coffee, P<0.05; Cow’s milk vs Goat’s milk + curcumin, P=NS; Cow’s milk vs Goat’s milk, P=NS; [underlined: SBP (mmHg), median (IQR)]; Within group: baseline, 5wk; Goat’s milk: 121.5 (113.5-128.0), 116.5 (110.0-123.0), P=0.157; Goat’s milk + curcumin: 128.0 (110.5-135.5), 117.0 (110.5-128.0), P=0.074; Goat’s milk + coffee: 122.0 (108.0-125.0), 118.0 (107.0-120.0), P=0.286; Cow’s milk: 122.5 (110.0-140.5), 112.5 (105.3-143.8), P=0.037; Between group: difference at 5wk; P=0.924; [underlined: DBP (mmHg), median (IQR)]; Within group: baseline, 5wk; Goat’s milk: 80.0 (71.8-86.3), 77.0 (70.5-81.5), P=0.068; Goat’s milk + curcumin: 76.0 (69.0-85.5), 75.0 (66.8-83.3), P=0.540; Goat’s milk + coffee: 74.0 (70.0-78.0), 71.0 (67.5-77.3), P=0.371; Cow’s milk: 74.0 (67.0-93.3), 75.0 (61.5-92.8), P=0.134; Between group: difference at 5wk; P=0.585 | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Most of the participants are female, so the findings may not be generalizable to men.; Funding: National Science and Technology Development Agency (Thailand)

a Abbreviations: β: beta; %tile: percentile; BMI: body mass index; BP: blood pressure; CE: cholesterol esters; CHO: carbohydrate; CI: confidence interval; CHD: Coronary Heart Disease; CVD: Cardiovascular Disease; d: day; DBP: diastolic blood pressure; FFQ: food frequency questionnaire; g: grams; HDL: high-density lipoprotein; hx: history; LDL: low-density lipoprotein; mg: milligram; ml: milliliter; mmol: millimoles; mo: months; MI: Myocardial Infarction; MUFA: monounsaturated fatty acids; NA: not applicable; NIH: National Institutes of Health; NR: not reported; NS: non-significant; PCS: prospective cohort study; PRO: Protein; PUFA: poly-unsaturated fatty acids; RCT: Randomized controlled trial; REF: reference; SBP: systolic blood pressure; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SFA: Saturated fatty acids; SSB: sugar-sweetened beverages; TG: triglycerides; wk: week; wks: weeks; y: year

Table 43 Risk of bias for randomized controlled trials examining the relationship between substituting one form of dairy with another form^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (effect of assignment) | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of reported results | Overall risk of bias
Rosqvist, 2015^33^ | SOME CONCERNS | NOT APPLICABLE | LOW | NOT APPLICABLE | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Schlienger, 2014^32^ | SOME CONCERNS | NOT APPLICABLE | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Phosat, 2022^30^ | SOME CONCERNS | NOT APPLICABLE | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Nestel, 2005^20^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Hjerpsted, 2011^11^ | SOME CONCERNS | LOW | NOT APPLICABLE | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Brassard, 2017^6^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 44 Risk of bias for observational studies examining the relationship between substituting one form of dairy with another form^b^

| Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Laursen, 2018^43^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Laursen, 2019^44^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Laursen, 2022^45^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Kvist, 2020^42^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 45 Evidence examining the relationship between dairy compared to carbohydrate or protein comparator in adults^a^

Study and Participant Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Methodological Considerations
Meyer, 2004^17^; RCT-crossover, Australia; Analytic N = 23; Adequately powered: Yes; Study aims: To investigate the effects of regular consumption of foods containing whole soybean extracts on cardiovascular benefits; Participant characteristics:; - Age: 54.0 (1.8) y; - Female: 43%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 26.2 (0.6); - Health Status: 100% Hypercholesterolemia (mild) and/or hypertension; 100% TC >5.5 mmol/l or BP >140/90 and not taking medication for either condition; Excluded pre-menopausal women; those with plasma cholesterol <5.5 mmol/L or BP <140/90; those taking medication for cholesterol or BP | Intervention and Comparators:; - Soy: 4 svg/d of soy milk and/or low-fat soy yogurt; - Dairy: 4 svg/d (250 ml/svg) of low-fat milk and/or low-fat yogurt; Intervention duration: 5 wk (No washout); Other Group Differences: Significant differences between groups (p<0.05): SFA (dairy > soy); MUFA (dairy > soy); PUFA (dairy < soy); NS between groups: total energy, protein, carbohydrate, fat; Compliance: Mean intake (svg/day): Dairy: 3.68 (SD: 0.10), Soy: 3.54 (0.14), p=NS; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood lipids after 5 wk trial | [underlined: LDL (mmol/L), Mean (SEM)]; Dairy: 3.98 (0.21); Soy: 3.92 (0.21); Difference: −0.05 (0.10), p=NS; [underlined: HDL (mmol/L), Mean (SEM)]; Dairy: 1.28 (0.07); Soy: 1.35 (0.07); Difference: 0.06 (0.03), p=NS; [underlined: TG (mmol/L), Mean (SEM)]; Dairy: 1.25 (0.13); Soy: 1.22 (0.13); Difference: −0.02 (0.10), p=NS; [underlined: SBP (mmHg), Mean (SEM)]; Dairy: 133 (3.5); Soy: 132 (2.9); Change from dairy to soy: −0.60 (1.7), p=NS; [underlined: DBP (mmHg), Mean (SEM)]; Dairy: 79 (2.3); Soy: 77 (1.9); Change from dairy to soy: −2.00 (1.7), p=NS | Key confounders accounted for: NA; Other covariates accounted for: Dietary fibre, cholesterol, total fat, total saturated fat, total polyunsaturated fat, total energy, amount of yoghurt consumed, whether subject was on soy first or dairy first.; Limitations: Participant and researchers not blinded; Funding: So Natural Foods; Australian Research Council
Kurowska, 1997^14^; RCT-crossover, Canada; Analytic N = 34; Adequately powered: No; Study aims: Determine whether plasma levels of TC and LDL can be reduced by substituting dietary soybean products for cow’s milk products containing comparable amounts of protein and fat, and assess the contribution of soy oil alone toward any effect on the lipoprotein profile attributed to soybean products; Participant characteristics:; - Age: 55 (11) y; - Female: 50%; - Race and/or ethnicity: NR; - SEP: NR; - Mean body weight: 80 (14) kg; - Health Status: 100% Hypercholesterolemia (moderately elevated); Excluded those with moderate hypercholesterolemia. Included those with or who: initial fasting plasma TG within normal range (0.8-3.7 mmol/L); habitual milk drinkers (2+ glasses/day); free of thyroid disorders, kidney Dz, DM; alcohol intake ≥ 2 drinks/day. Participants taking cholesterol medications discontinued 2-3 wks before the study | Intervention and Comparators:; - Soybean milk (3 cups) + soybean dessert (basal diet + soy: 17.8g SFA; 29% energy from total fat); - Skim milk (3 cups) + 1/2 cup skim milk dessert + 1 tbsp soy oil/day; - Milk (2%) (3 glasses) + low-fat milk dessert (basal diet + milk: 24.7 g SFA; 29% energy from total fat); Intervention duration: 4 wk (2 wk washout); Other Group Differences: All periods contained: 31g PRO, 18g fat; Compliance: Yes; 3-d food records collected during each diet period, dietitian ensured comprehension and compliance; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting | [underlined: LDL (mmol/L), Mean (SD)]; Baseline: 4.45 (0.95); Milk: 4.36 (1.07); Soy: 4.26 (1.04); P>0.05; [underlined: HDL (mmol/L), Mean (SD)]; Baseline: 1.31 (0.32); Milk: 1.30 (0.41); Soy: 1.40 (0.28); P=0.04; [underlined: TG (mmol/L), Mean (SD)]; Baseline: 1.75 (0.64); Milk: 1.85 (0.72); Soy: 1.94 (0.83); P>0.05; [underlined: SBP (mmHg), Mean (SD)]; Baseline: 131 (17); Milk: 123 (15); Soy: 128 (15); P=0.04; [underlined: DBP (mmHg), Mean (SD)]; Baseline, 77 (10); Milk: 73 (10); Soy: 77 (8); P=0.021 | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: All analyses examined differences in change from baseline between diet periods (rather than timeby-condition interactions); Funding: Industry: Alpro Natural Soyfoods (Wavelgem, Belgium)
Pei, 2017^29^; RCT-parallel, United States; Analytic N = 120; Adequately powered: NR; Study aims: To determine whether low-fat yogurt reduces biomarkers of chronic inflammation and endotoxin exposure in women; Participant characteristics:; - Age: ~25 (1) y for those with normal weight, ~34 (2) y for those with obesity; 21-55 y; - Female: 100%; - Race and/or ethnicity: NR; - SEP: NR; - BMI ~23 kg/m2 in those with normal weight and ~34 kg/m2 in those with obesity; - Health Status: 50% with BMI 30-40 kg/m2; Excluded those <21 or >55 y; unstable body weight in previous 2mo; CVD, diabetes or arthritis; being treated for cancer; taking antiinflammatory drugs or estrogen replacement therapy; on a slimming, vegetarian, or vegan diet; taking dietary supplements or smoking; allergic to soy, egg, or milk; pregnant, lactating, or seeking to become pregnant | Intervention and Comparators:; - Soya pudding: dairy-free and unfermented; matched for macronutrient, micronutrient, energy content, and texture (ZenSoy); 324g daily; - Dairy yogurt: commercially available lowfat yogurt (Yoplait); 339g (12oz) daily; Intervention duration: 9 wk (2 wk washout); Other Group Differences: No notable differences in nutrients between the groups To avoid confounding by probiotic or dairy product consumption, the participants were instructed to restrict consumption of dietary supplements, fermented foods and limit their dairy product consumption to ≤4 servings/d for 2 weeks before the intervention (washout period, weeks −2-0) and throughout the intervention.; Compliance: Yes, all groups showed similar compliance (>95%) based on dietary records and weekly collection of lids/cups; Outcome(s): SBP, DBP; Outcome assessment methods and timing: Blood pressure measured twice at least 3min apart at baseline, 3wk, 6k, and 9wk | [underlined: Change in SBP (mmHg), Mean (SE)]; Within group: 3wk, 6wk, 9wk; Control, normal weight: 0.23 (1.48), −1.73 (1.04), 0.33 (1.57); Control, obesity: 2.57 (1.22), 1.71 (1.39), 1.12 (1.70); Yogurt, normal weight: 0.13 (1.29), −0.72 (1.46), 2.45 (1.64); Yogurt, obesity: −1.13 (1.48), −0.68 (1.29), −0.25 (1.17); P-treatment=0.1233; P-treatment x obesity = 0.5015; [underlined: Change in DBP (mmHg), Mean (SE)]; Within group: 3wk, 6wk, 9wk; Control, normal weight: 1.57 (1.22), −1.48 (1.05), 0.15 (1.14); Control, obesity: 0.78 (0.91), 1.02 (0.91), 0.77 (1.22); Yogurt, normal weight: 0.02 (0.77), 0.50 (1.09), 0.75 (1.11); Yogurt, obesity: −2.82 (0.90), −2.10 (0.83), −1.90 (0.95); P-treatment=0.0188; P-treatment x obesity = 0.0902 | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Participants were not blinded; No details on saturated fat content; Only pre-menopausal women were included, so the findings many not be generalizable.; Funding: National Dairy Council
Raziani, 2017^31^; RCT-parallel, Denmark; Analytic N = 164 (Regular-fat cheese: n=50, Reduced-fat cheese: n=51, Carbohydrate: n=49); Adequately powered: Yes; Study aims: To compare the effects of regular-fat cheese with an equal amount of reduced-fat cheese and an isocaloric amount of carbohydrate-rich foods on LDL cholesterol and risk factors for the metabolic syndrome.; Participant characteristics:; - Age: ~54 y; - Female: 66%; - Race and/or ethnicity: NR; - SEP: NR; - BMI ~29 (3); - Health Status: 100% with ≥2 MetS risk factors; Excluded chronic diseases (known T2D, CVD, or other chronic diseases that could affect the study outcome), milk allergy, use of prescription medicine that could affect results of the study (e.g., lipid-lowering agents), >10hr of strenuous physical activity/wk, drug and alcohol abuse, blood donation <1mo before study commencement or during the study period, simultaneous participation in other clinical studies, pregnant or lactating woman or women who were planning to become pregnant during the intervention, inability to comply with the procedures required by the protocol. | Intervention and Comparators:; - Reduced-fat cheese: 40g of reduced-fat Danbo (13% fat) and 40g sharp cheddar (16% fat) cheese providing 15g Fat and 8.9g SFA; - Carbohydrate control: 90g white-wheat bread and 25g sugar-sweetened jam providing 1.9g Fat and 0.2g SFA; Compared to the regular-fat cheese, the carbohydrate control contained the same amount of energy and the reduced-fat cheese contained ~17% less energy.; During a 2wk run-in, all participants received 250 mL/d of skimmed milk and were asked to refrain from consuming other dairy products. Regular-fat cheese: 40g of regular-fat Danbo (25% fat) and 40g of sharp cheddar (32% fat) cheese providing 23.4g Fat and 14.4g SFA; Intervention duration: 12 wk; Other Group Differences: All participants were provided with 250mL of skimmed milk (0.1% fat) per day throughout intervention and asked not to consume any other dairy products. Remaining part of participant’s habitual diet was not controlled and they were asked to maintain their usual diets. NS difference in fiber intake from 3d weighed dietary records at 12wk. Energy not matched but no significant differences found between groups.; Compliance: Yes, >95% in all groups and NS differences between groups in % of test food consumed compared with test food handed to participants; Baseline intake of study foods: All drank 250 mL/d of skimmed milk (2wk run-in); Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood collection and blood pressure (3 consecutive measurements, mean of last 2 was recorded) at baseline, 6wk, and 12wk | [underlined: LDL (mmol/L)]; Within group: Mean (SD) at baseline, Mean (SEM) at 12wk; Reduced-fat cheese: 3.36 (0.88), 3.45 (0.13); Regular-fat cheese: 3.34 (0.81), 3.51 (0.11); Between group: change over 12wk, Mean (SEM); Reduced-fat cheese: 0.09 (0.08); Regular-fat cheese: 0.17 (0.07); P=0.42; [underlined: HDL (mmol/L)]; Within group: Mean (SD) at baseline, Mean (SEM) at 12wk; Reduced-fat cheese: 1.42 (0.33), 1.46 (0.04); Regular-fat cheese: 1.39 (0.37), 1.45 (0.06); Between group: change over 12wk, Mean (SEM); Reduced-fat cheese: 0.05 (0.02); Regular-fat cheese: 0.06 (0.02); P=0.86; [underlined: TG (mmol/L)]; Within group: Mean (SD) at baseline, Mean (SEM) at 12wk; Reduced-fat cheese: 1.26 (0.53), 1.23 (0.07); Regular-fat cheese: 1.31 (0.59), 1.42 (0.11); Between group: change over 12wk, Mean (SEM); Reduced-fat cheese: −0.03 (0.07); Regular-fat cheese: 0.11 (0.09); P=0.11; [underlined: SBP (mmHg)]; Within group: Mean (SD) at baseline, Mean (SEM) at 12wk; Reduced-fat cheese: 128.5 (15.2), 125.2 (2.2); Regular-fat cheese: 131.7 (15.1), 130.5 (1.9); Between group: change over 12wk, Mean (SEM); Reduced-fat cheese: −3.2 (1.3); Regular-fat cheese: −1.1 (1.4); P=0.17; [underlined: DBP (mmHg)]; Within group: Mean (SD) at baseline, Mean (SEM) at 12wk; Reduced-fat cheese: 83.1 (9.5), 81.1 (1.3); Regular-fat cheese: 84.7 (9.1), 83.3 (1.1); Between group: change over 12wk, Mean (SEM); Reduced-fat cheese: −2.0 (0.7); Regular-fat cheese: −1.4 (0.7); P=0.50; [underlined: LDL (mmol/L), Change over 12wk, Mean (SEM)]; Carbohydrate control: 0.03 (0.06); Regular-fat cheese: 0.17 (0.07); P=0.17; [underlined: HDL (mmol/L), Change over 12wk, Mean (SEM)]; Carbohydrate control: 0.01 (0.03); Regular-fat cheese: 0.06 (0.02); P=0.07; [underlined: TG (mmol/L), Change over 12wk, Mean (SEM)]; Carbohydrate control: 0.11 (0.06); Regular-fat cheese: 0.11 (0.09); P=0.88; [underlined: SBP (mmHg), change over 12wk, Mean (SEM)]; Carbohydrate control: −2.0 (1.5); Regular-fat cheese: −1.1 (1.4); P=0.21; [underlined: DBP (mmHg), change over 12wk, Mean (SEM)]; Carbohydrate control: −1.9 (0.7); Regular-fat cheese: −1.4 (0.7); P=0.77 | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Participants were not blinded; Funding: Danish Dairy Research Foundation; Danish Agriculture and Food Council; National Dairy Council (United States); Dairy Farmers of Canada; Centre National Interprofessionel de l’Economie Laitière; Dairy Australia; Nederlandse Zuivel Organisatie
Haring, 2014^38^; PCS, United States, ARIC; Analytic N = 12,066; Participant characteristics:; - Age: ~53.8 (5.7)y; 45-64y; - Female: 56%; - Race and/or ethnicity: 77% White; 23% Black; - SEP: 79% High school graduates; - BMI 27.1 kg/m2; - Health Status: 29% HTN; Excluded participants with selfreported diabetes, fasting blood glucose ≥126 mg/dL, non-fasting blood glucose ≥200 mg/dL or use of diabetes medication, a history of myocardial infarction, stroke, heart failure, coronary bypass surgery, angioplasty or with missing data on covariates of interest.; Participants that reported implausible energy intake or incomplete dietary information were excluded; Current smoker: ~26% | Exposure and Comparators:; Continuous (1 svg/d substitution); - High-fat dairy; - Low-fat dairy; - Fish/seafood; - Eggs; - Nuts; - Legumes; Exposure assessment method: FFQ at baseline and ~6y follow-up (cumulative average); Baseline intake of study foods: Median: 0.4 svg/d of high-fat dairy, 0.4 svg/d of lowfat dairy, 0.4 svg/d of processed meat, 0.5 svg/d of red meat, 0.3 svg/d of poultry; Outcome(s): CHD (definite or probable MI, or CHD death); Outcome assessment methods and timing: Adjudicated using information from study visits, yearly telephone follow-up calls, review of hospital discharge lists and medical charts, death certificates, next-ofkin interviews, and physician-completed questionnaires at 22 y follow-up | [underlined: CHD per 1 svg/d substitution, HR (95% CI)]; Low-fat dairy for high-fat dairy: 0.93 (0.84, 1.02); [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy; Fish/seafood for high-fat dairy: 0.94 (0.75, 1.19); Low-fat dairy; Fish/seafood for low-fat dairy: 1.02 (0.80, 1.28); [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy; Eggs for high-fat dairy: 0.89 (0.75, 1.06); Nuts for high-fat dairy: 0.90 (0.78, 1.03); Legumes for high-fat dairy: 0.93 (0.73, 1.19); Low-fat dairy; Eggs for low-fat dairy: 0.96 (0.81, 1.14); Nuts for low-fat dairy: 0.97 (0.84, 1.11); Legumes for low-fat dairy: 1.01 (0.79, 1.28); [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy for processed meat: 1.04 (0.90, 1.20); High-fat dairy for red meat: 0.91 (0.74, 1.12); High-fat dairy for poultry: 1.12 (0.90, 1.40); Low-fat dairy for processed meat: 0.96 (0.84, 1.11); Low-fat dairy for red meat: 0.84 (0.68, 1.05); Low-fat dairy for poultry: 1.04 (0.83, 1.30) | Key confounders accounted for: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (all the food items in the table, fiber intake), total energy intake; Key confounders NOT accounted for: None; Other covariates accounted for: Study center, systolic blood pressure, use of antihypertensive and/or lipid lowering medication, HDL, total cholesterol, carbohydrate intake, magnesium intake; Limitations: Only Black and White participants are included, so the findings are not entirely generalizable. No preregistered data analysis plan; Funding: NHLBI/NIH; German Research Foundation; University of Wurzburg
Maki, 2013^16^; RCT-crossover, United States; Analytic N = 62; Adequately powered: Yes (for SBP); Study aims: To assess the effects of consuming low-fat dairy versus nondairy products on fasting and postprandial blood pressures, endothelial function, and fasting lipoprotein lipids in men and women with prehypertension or stage 1 hypertension who were not receiving antihypertensive medication.; Participant characteristics:; - Age: 54.7 (1.2)y; 20-69y; - Female: 45%; - Race and/or ethnicity: 68% NonHispanic White; 26% Black/African American; 6% Asian or Pacific Islander; - SEP: NR; - BMI 29.2 (0.6) kg/m2; - Health Status: 100% with Pre-HTN or Stage 1 HTN; 84% Pre-HTN; 16% Stage 1 HTN; Excluded those with BMI <18.5 or ≥40kg/m2; SBP ≥160 or DBP ≥100mmHg; habitual intake of >2 svg/d of dairy; those with CHD, DM, or fasting glucose ≥126 mg/dL; clinical signs of atherosclerosis or multiple risk factors conferring >20% probability for developing coronary artery disease within 10y (Framingham Risk Score); clinically important endocrine, cardiovascular, pulmonary, biliary or gastrointestinal disorders; cancer in the prior 2y (except for nonmelanoma skin cancer); major trauma or surgical event within 2mo; active infection or taking antibiotic therapy; extreme dietary habits or a history of an eating disorder; recent history or strong potential for alcohol or substance abuse; latex allergy or allergy/sensitivity to study foods; digital deformities that prevent endothelial function measurements; abnormal laboratory test at screening; within 4wk of screening, no medications or dietary supplements affecting BP or endothelial function, unstable use of lipid-altering supplements/ drugs; weight-altering drugs, weight loss supplements/foods, or meal replacement programs or products | Intervention and Comparators:; - Dairy, low-fat; 1 svg/d each of 1% fluid milk (8oz), part-skim mozzarella string cheese (1oz), and low-fat strawberry yogurt (6oz) providing 290kcal, 35g CHO, 21g PRO, 8.5g fat; - CHO: non-dairy; 1 svg/d each of apple juice (6.75 fl oz), pretzels (0.9oz), chocolate chip cereal bar (23g) providing 300kcal, 64g CHO, 3g PRO, 1.5g fay; All participants were instructed to consume ≤1 serving/day of other dairy foods during each treatment period.; Intervention duration: 5 wk (≥2 wk washout); Other Group Differences: Dairy treatment: greater % of protein, total fat, SFA, calcium, magnesium, and potassium, and significantly less carbohydrate and dietary fiber compared to the nondairy treatment; Compliance: Yes, >98% based on daily study product log and returned unconsumed servings; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood collection at baseline and after each 5wk intervention period. Blood pressure measured at baseline, 5wk, 12wk and before and after test meal for 5wk and 12wk | [underlined: LDL (mg/dL), Mean (SEM)]; Baseline: 132.1 (3.8); % change over 5wk; CHO: −3.3 (1.1); Dairy: −2.9 (1.3); P=0.782; [underlined: HDL (mg/dL), Mean (SEM)]; Baseline: 50.6 (1.9); % change over 5wk; CHO: −2.4 (1.6); Dairy: −0.9 (1.3); P=0.459; [underlined: TG (mg/dL), Mean (SEM)]; Baseline: 138.4 (8.8); % change over 5wk; CHO: 6.5 (3.5); Dairy: 3.3 (3.7); P=0.368; [underlined: SBP (mmHg)]; Baseline, Mean (SEM): 129.8 (0.9); Premeal to postmeal after each 5wk condition (total AUC), Mean; CHO: 124.9; Dairy: 126.3; P=0.436; [underlined: DBP (mmHg)]; Baseline, Mean (SEM): 80.8 (0.9); Premeal to postmeal after each 5wk condition; (total AUC), Mean; CHO: 75.7; Dairy: 76.5; P=0.623; Subgroup analyses were non-significant, results NR (prehypertension vs. stage 1, age, BMI, and race and/or ethnicity) | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: Inadequate information on randomization concealment and betweengroup baseline differences; Participants not blinded; No preregistered data analysis plan; Funding: Dairy Research Institute
Beavers, 2010^26^; RCT-parallel, United States; Analytic N = 32; Adequately powered: Yes; Study aims: To examine the effects of soymilk consumption on plasma lipid levels in a postmenopausal female population.; Participant characteristics:; - Age: 54 (3.4) y; 40-60 y; - Female: 100%; - Race and/or ethnicity: NR; - SEP: NR; - BMI ~25.8 (3.9) kg/m2; - Health Status: Generally healthy; 100% postmenopausal; LDL: ~111 (22); HDL: ~65 (15); TG: ~108 (81); VO2 max: ~25.6 (4.8); Included postmenopausal women; physical active but not trained;; Excluded use of HRT; CAD and/or other significant uncontrolled cardiovascular, renal, hepatic, gastrointestinal, mental, and endocrine disorders; BMI <19 or >35kg/m2; active smoking; >2/d alcoholic drinks; dietary supplements affecting antioxidant status (excluding multivitamins) | Intervention and Comparators:; - Dairy milk (N=16): 3 svg/d reduced-fat organic dairy milk (1 svg = 8 fluid oz; providing 120 kcal, 4.5g fat, 8g PRO, and 12g CHO); - Soymilk (N=16): 3 svg/d vanilla-flavored soymilk (1 svg = 8.25 fluid oz; providing 130 kcal, 4g fat, 6g PRO, and 19g CHO); All participants had a 2wk run-in phase before the 4wk intervention in which they were instructed to limit dairy (avoid milk completely and limit other dairy to 2 svg/d) and avoid isoflavone-containing soy products; Intervention duration: 4 wk; Other Group Differences: Beverages varied slightly in kcal, fat, and protein; and more substantially in CHO; Group x time interaction for fiber (higher in soymilk) and cholesterol (higher in dairy milk); Compliance: Yes, compliance logs; Outcome(s): LDL, HDL, TG; Outcome assessment methods and timing: Fasting blood collection at baseline and 4wk | [underlined: LDL (mg/dL), Mean (SD)]; Within group: baseline, 4wk; Soymilk: 106.56 (24.22), 111.4 (30.4); Dairy milk: 115.62 (20.21), 122.6 (33.5); Between group: difference at 4wk p = NS; [underlined: HDL (mg/dL), Mean (SD)]; Within group: baseline, 4wk; Soymilk: 63.06 (12.01), 62.7 (13.3); Dairy milk: 66.81 (17.21), 68.1 (15.3); Between group: difference at 4wk p = NS; [underlined: TG (mg/dL), Mean (SD)]; Within group: baseline, 4wk; Soymilk: 103.50 (79.35), 105.9 (72.8); Dairy milk: 113.25 (82.63), 112.4 (62.8); Between group: difference at 4wk p = NS; Sensitivity analyses removing non-compliant participants (n=1), those on cholesterol-lowering meds, or with dyslipidemia did not show different results | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: No preregistered data analysis plan; Funding: White-Wave Foods, Inc.
van Meijl, 2011^23^; RCT-crossover, The Netherlands; Analytic N = 35; Adequately powered: NR; Study aims: To investigate the effects of daily consumption of low-fat dairy products on metabolic risk parameters in men and women with overweight and obesity; Participant characteristics:; - Age: 49.5 (13.2) y; - Female: 71%; - Race and/or ethnicity: NR; - SEP: NR; - BMI 32.0 (3.8) kg/m2; - Health Status: Overweight/Obesity;; Baseline values (mmol/L), Mean (SD); Excluded those with BMI ≤27 kg/m2 and/or waist circumference ≤88 cm in women or ≤102 cm in men; active CVD, familial hypercholesterolemia, or severe medical conditions that would interfere with study; alcohol or drug abuse; pregnant or breastfeeding; unstable body weight during last 3mo; dairy consumption ≥500 g/d | Intervention and Comparators:; - Dairy: 500mL low-fat milk (1.5%) and 150g low-fat yogurt (1.5%) per day; providing 358.5kcal, 24.4g PRO, 9.8g fat, 6.3g SFA; - CHO: 600mL fruit juice and 43g fruit biscuits (3 pieces) per day, providing 406.3kcal, 2.8g PRO, 3.8g fat, 1.6g SFA; Intervention duration: 8 wk (≥2wk washout); Other Group Differences: Energy content of intervention vs. control foods similar, and total energy did not differ between conditions. Significant differences in: Pro, total fat, SFA, MUFA, CHO; Compliance: Yes, near 100% based on return of uneaten food products; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood collection and blood pressure measured at baseline, 4, 7, and 8 weeks | [underlined: LDL (mmol/L), Mean (SD)]; Within group: change over 8wk; Dairy: 4.12 (0.98); CHO: 4.09 (0.93); Between group: absolute change 0.03 (0.43), 95% CI: −0.12, 0.18 P=0.667; [underlined: HDL (mmol/L), Mean (SD)]; Within group: change over 8wk; Dairy: 1.40 (0.34); CHO: 1.44 (0.34); Between group: absolute change −0.04 (0.09), 95% CI: −0.07, 0.01 P=0.021; [underlined: TG (mmol/L), Mean (SD)]; Within group: change over 8wk; Dairy: 1.46 (0.61); CHO: 1.50 (0.56); Between group: absolute change −0.04 (0.37), 95% CI: −0.16, 0.09 P=0.552; [underlined: SBP (mmHg), Mean (SD)]; Within group: change over 8wk; CHO: 131.3 (18.3); Dairy: 128.4 (19.2); Between group: absolute change −2.91 (7.4), 95% CI: −5.45, −0.34 P=0.027; [underlined: DBP (mmHg), Mean (SD)]; Within group: change over 8wk; CHO: 87.0 (11.5); Dairy: 85.4 (10.2); Between group: absolute change −1.55 (5.2), 95% CI: −3.35, 0.25 P=0.090 | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: No information on randomization or allocation procedures; No power calculation; No preregistered data analysis plan; Funding: Dutch Dairy Association
Roy, 2019^22^; RCT-crossover, United States; Analytic N = 60; Adequately powered: Yes; Study aims: To determine if a dietary intervention that includes whole milk and full-fat dairy products reduces arterial blood pressure in adults with elevated blood pressure; Participant characteristics:; - Age: 58 (2)y; 22-77y; - Female: 53%; - Race and/or ethnicity: NR; - SEP: NR; - BMI 29 (0.8) kg/m2; - Health Status: 100% pre-HTN or stage 1 systolic HTN; Excluded those with overt chronic disease, lactose intolerance, dairy intake >3 svg/d, pregnancy or lactation, physical activity >3 times/wk, ethanol >294 g/wk, normotensive (SBP <120) | Intervention and Comparators:; - Dairy: 4 svg/d from any combination of 245g whole milk (5g SFA), 170g full-fat yogurt (4g SFA), and/or 43g Swiss cheese (8g SFA); (16-32 g SFA; 28-48 g total fat); - No dairy: 465g Silk coconut milk. 496g orange juice fortified with vitamin D and calcium, 57g of single-serve Planters salted peanuts, and 113g of single-serve cups of Motts applesauce (14 g SFA; 38g total fat); Intervention duration: 4 wk each (2wk washout); Other Group Differences: NS difference between groups for energy intake or total fat. Dairy group consumed less CHO (P=0.03) and fiber (P<0.001), and more PRO (P<0.001) compared to the non-dairy group.; Compliance: Yes, ≥94% based on consumption of laboratory-provided food items; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood collection and blood pressure measured at baseline and after each 4wk period | [underlined: LDL (mmol/L), Mean (SEM)]; Within group: baseline, 4wk; CHO/PRO (no dairy): 3.04 (0.12), 3.02 (0.12), P=NS; Dairy: 3.02 (0.12), 3.28 (0.12), P=NS; Time x Condition P-interaction=0.07; [underlined: HDL (mmol/L), Mean (SEM)]; Within group: baseline, 4wk; CHO/PRO (no dairy): 1.30 (0.07), 1.26 (0.06), P=NS; Dairy: 1.32 (0.06), 1.31 (0.06), P=NS; Time x Condition P-interaction=0.38; [underlined: TG (mmol/L), Mean (SEM]); Within group: baseline, 4wk; CHO/PRO (no dairy): 1.46 (0.12), 1.41 (0.12), P=NS; Dairy: 1.41 (0.12), 1.42 (0.12), P=NS; Time x Condition P-interaction=0.60; [underlined: SBP (mmHg), Mean (SEM)]; Within group: baseline, 4wk; CHO/PRO (no dairy): 136 (1), 133 (1), P=NS; Dairy: 135 (1), 133 (1), P=NS; P-interaction=0.734; [underlined: DBP (mmHg), Mean (SEM)]; Within group: baseline, 4wk; CHO/PRO (no dairy): 83 (1), 82 (1); Dairy: 83 (1), 82 (1); P-interaction=0.595 | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: None; Funding: National Dairy Council; Dairy Research Cluster Initiative (Agriculture and Agri-Food Canada, Dairy Farmers of Canada, the Canadian Dairy Network, and the Canadian Dairy Commission)
Crippa, 2018^9^; RCT-crossover, Italy; Analytic N = 30; Adequately powered: Yes; Study aims: The evaluate the effect of a daily dietary supplement consisting in a small amount (30 g/day) of Grana Padano cheese, in terms of the lowering of the blood pressure of mild-moderate hypertensive subjects.; Participant characteristics:; - Age: 52.3 (12.5)y; - Female: 43%; - Race and/or ethnicity: NR; - SEP: NR; - BMI 26.3 (4.7) kg/m2; - Health Status: 100% Mild/moderate HTN; Excluded those with SBP ≤140 and/or DBP ≤90 mmHg; <3mo of stable treatment (pharmacological and nonpharmacological) for HTN | Intervention and Comparators:; - Cheese: 30g Grana Padano cheese (SFA NR; ~8.8g lipids/30g); - CHO: placebo made with grated bread and added with purified Grana Padano cheese aroma, salts of sodium and calcium, and fat from groundnut oil in order to obtain same levels of salt and fat (SFA NR; ~8.8g lipids/30g); Intervention duration: 2 mo (no washout); Other Group Differences: Groups were similar in lipid content (28g per 100g), sodium (0.5g per 100g), and calcium (0.8g per 100g); Compliance: NR; Outcome(s): TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood collection and blood pressure measurements at baseline and after each 2mo period | [underlined: TG (mg/100mL), Mean (SD)]; CHO vs Cheese: Data NR, P=NS; [underlined: SBP (mmHg), Root mean square error]; CHO (placebo): −1.77; Cheese: −6.60; Mean difference: 4.83, P=0.0085; [underlined: DBP (mmHg), Root mean square error]; CHO (placebo): −1.77; Cheese: −5.33; Mean difference: 3.56, P=0.0126; Results were also provided for automated BP (measured without physician in the room) | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: No preregistered data analysis plan; Funding: Consorzio Grana Padano DOP (Desenzano del Garda, Bresica, Italy)
Brassard, 2017^6^; RCT-crossover, Canada; Analytic N = 92; Adequately powered: Yes; Study aims: To assess the impact of consuming equal amounts of SFA from cheese, butter vs. MUFA, PUFA and CHO on cardiometabolic risk factors; Participant characteristics:; - Age: 39.2 y; 18-65 y; - Female: 53%; - Race and/or ethnicity: 72% White; 8% Black; 8% Hispanic; 11% Asian; 2% Other; - SEP: NR; - BMI: 30.79 kg/m2; - Health Status: 100% Abdominal obesity; All participants with HDL below the age- and sex-specific 75th percentiles (≤1.34 and ≤1.53 mmol/L for men and women, respectively); Excluded individuals with high HDLcholesterol concentrations, a history of CVD, type 2 diabetes, or monogenic dyslipidemia; the use of medications for hypertension, hyperlipidemia, or glycemic control; uncontrolled endocrine disorder such as hypothyroidism or hyperthyroidism; smoking; a Framingham-calculated CAD risk score >20%; any food allergies or aversion to foods that were included in the menu; particular nutritional habits such as vegetarianism; and women with menstrual irregularities including those who were experiencing perimenopause. Participants not allowed to use anti-inflammatory drugs.; Included participants with waist circumference ≥94 and ≥80 cm for men and women, respectively, and have HDL-cholesterol concentrations below the age- and sex-specific 75th percentiles (≤1.34 and ≤1.53 mmol/L for men and women, respectively) | Intervention and Comparators:; - MUFA: diet rich in MUFA (5.8% SFA; 19.6% MUFA; 4.8% PUFA; 51.9% CHO); - PUFA: diet rich in PUFA (5.8% SFA; 12.6% MUFA; 11.5% PUFA; 51.9% CHO); - CHO: high CHO, low- fat (5.8% SFA; 12.6% MUFA; 4.8% PUFA; 58.9% CHO); - Cheese: 90 g/2500 kcal (12.6% SFA; 12.5% MUFA; 4.8% PUFA; 51.9% CHO); - Butter: 48.9 g/2500 kcal (12.4% SFA; 12.3% MUFA; 4.8% PUFA; 52% CHO); Intervention duration: 4 wk each (≥24d washout period); Other Group Differences: SFA in butter and cheese was matched.; Diets were identical in terms of energy, protein, cholesterol, sodium and fiber contents; calcium and potassium were higher in the cheese condition than the other 4.; Compliance: Yes; Participants filled checklist. Excluded participants from the treatment phases where compliance was <80%; Compliance: 98.7% ± 2.4% after the exclusion of non-compliant subjects; Outcome(s): LDL, HDL, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood measured twice on consecutive days at the end of each dietary phase. Mean of the two measurements was used | [underlined: LDL (mmol/L), Mean (SD)]; Cheese: 3.19 (0.81); Butter: 3.30 (0.84); MUFA: 3.03 (0.78); PUFA: 2.84 (0.69); Cheese vs. MUFA: P<0.05; Butter vs. MUFA: P<0.05; Cheese vs. PUFA: P<0.05; Butter vs. PUFA: P<0.05; [underlined: HDL (mmol/L), Mean (SD)]; Cheese: 1.10 (0.19); Butter: 1.11 (0.21); MUFA: 1.10 (0.19); PUFA: 1.10 (0.20); Cheese vs. MUFA; Cheese vs. PUFA; Butter vs. PUFA; Butter vs. MUFA: P>0.05; [underlined: TG (mmol/L), Mean (SD)]; Cheese: 1.43 (0.70); Butter: 1.36 (0.73); MUFA: 1.38 (0.67); PUFA: 1.30 (0.62); Cheese vs. PUFA: P<0.05; Cheese vs. MUFA; Butter vs. PUFA; Butter vs. MUFA: P>0.05; Results were also provided from ITT with similar findings; [underlined: SBP (mmHg), Mean (SD)]; Cheese: 109.9 (13.4); Butter: 109.0 (12.4); MUFA: 111.4 (12.9); PUFA: 109.9 (13.0); P (between group)>0.05; [underlined: DBP (mmHg), Mean (SD)]; Cheese: 70.0 (10.4); Butter: 68.9 (9.8); MUFA: 68.7 (9.8); PUFA: 68.8 (11.3); P (between group)>0.05; Results were also provided from ITT with similar findings; [underlined: LDL (mmol/L), Mean (SD)]; Cheese: 3.19 (0.81); Butter: 3.30 (0.84); CHO: 3.11 (0.79); Cheese vs. CHO: P<0.05; Butter vs. CHO: P<0.05; [underlined: HDL (mmol/L), Mean (SD)]; Cheese: 1.10 (0.19); Butter: 1.11 (0.21); CHO: 1.06 (0.19); [underlined: Cheese vs. CHO: P<0.05]; [underlined: Butter vs. CHO: P<0.05]; [underlined: TG (mmol/L), Mean (SD)]; Cheese: 1.43 (0.70); Butter: 1.36 (0.73); CHO: 1.46 (0.71); Butter vs. CHO: P<0.05; Cheese vs. CHO: P>0.05; Results were also provided from ITT with similar findings; [underlined: SBP (mmHg), Mean (SD)]; Cheese: 109.9 (13.4); Butter: 109.0 (12.4); CHO: 109.8 (12.6); P (between group)>0.05; [underlined: DBP (mmHg), Mean (SD)]; Cheese: 70.0 (10.4); Butter: 68.9 (9.8); CHO: 69.9 (10.0); P (between group)>0.05; Results were also provided from ITT with similar findings; [underlined: LDL (mmol/L), Mean (SD)]; Cheese: 3.19 (0.81); Butter: 3.30 (0.84); P<0.05; [underlined: HDL (mmol/L), Mean (SD)]; Cheese: 1.10 (0.19); Butter: 1.11 (0.21); P>0.05; [underlined: TG (mmol/L), Mean (SD)]; Cheese: 1.43 (0.70); Butter: 1.36 (0.73); P<0.05; Results were also provided from ITT with similar findings; [underlined: SBP (mmHg), Mean (SD)]; Cheese: 109.9 (13.4); Butter: 109.0 (12.4); P>0.05; [underlined: DBP (mmHg), Mean (SD)]; Cheese: 70.0 (10.4); Butter: 68.9 (9.8); P>0.05; Results were also provided from ITT with similar findings | Key confounders accounted for: NA; Other covariates accounted for: None; Limitations: High drop-out rates; Funding: Fondation du Centre Hospitalier Universitaire de Québec – Université Laval; Green Fund of the Government of Québec
Keller, 2020^41^; PCS, United States, Harvard Pooling; Project (HPP) of Diet and Coronary Disease; Analytic N = 274,754 (coronary events); 280,886 (coronary deaths); Participant characteristics:; - Age: 54.3 y; ≥35 y; - Female: 76%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: NR; - Health Status: Generally healthy and without CVD or diabetes; ≥35 years at baseline. Excluded those with Hx CVD, DM, Cx; extreme energy intake (< or > 3 SDs) | Exposure and Comparators:; - Sugar-sweetened beverages (SSB): carbonated/non-carbonated and caffeinated/non-caffeinated sodas, sport drinks, and fruit drinks with any type of added sugar; 1 svg = 355mL; - Whole-fat milk: non-sweetened whole-fat cow milk; 1 svg = 355mL; - Low-fat milk: non-sweetened low-fat cow milk; 1 svg = 355mL; Exposure assessment method: FFQ once at baseline; Baseline intake of study foods: mL, Mean (SD); women, men; Whole milk: 42.28 (120.48); 96.35 (221.81); Low-fat milk: 179.10 (224.82); 227.47 (268.47); Outcome(s): CHD events (any first incident CHD event, including fatal CHD); Coronary death (total incident CHD death); Outcome assessment methods and timing: Standardized criteria, questionnaires supplemented by medical records reviewed by physicians at 8.2 y (median) follow-up | [underlined: Coronary deaths by 1 svg substitution, HR] [underlined: (95% CI)]; Whole-fat milk for SSB; All: 1.04 (0.90, 1.20); Women: 1.32 (1.02, 1.71); Men: 0.92 (0.77, 1.10); Low-fat milk for SSB; All: 0.99 (0.88, 1.12); Women: 0.97 (0.78, 1.20); Men: 1.00 (0.87, 1.16); [underlined: Coronary events by 1 svg substitution, HR (95% CI)]; Whole-fat milk for SSB; All: 0.97 (0.88, 1.06); Women: 1.16 (0.98, 1.37); Men: 0.90 (0.81, 1.00); Low-fat milk for SSB; All: 0.96 (0.90, 1.03); Women: 0.96 (0.84, 1.08); Men: 0.97 (0.88, 1.05) | Key confounders accounted for: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (cereal fibers, trans-fat, PUFA/SFA ratio), total energy intake; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: Baseline HTN, high cholesterol; Limitations: Moderate/substantial heterogeneity between cohorts for whole-milk analyses but data NR by cohort; Exposure measured at baseline only; No preregistered data analysis plan; Funding: NHLBI

a Abbreviations: β: beta; %tile: percentile; BMI: body mass index; BP: blood pressure; CE: cholesterol esters; CHO: carbohydrate; CI: confidence interval; CHD: Coronary Heart Disease; CVD: Cardiovascular Disease; d: day; DBP: diastolic blood pressure; FFQ: food frequency questionnaire; g: grams; HDL: high-density lipoprotein; hx: history; LDL: lowdensity lipoprotein; MI: Myocardial Infarction; mg: milligram; ml: milliliter; mmol: millimoles; mo: months; MUFA: monounsaturated fatty acids; NA: not applicable; NIH: National Institutes of Health; NR: not reported; NS: non-significant; PCS: prospective cohort study; PUFA: polyunsaturated fatty acids; RCT: Randomized controlled trial; REF: reference; SBP: systolic blood pressure; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SFA: Saturated fatty acids; SSB: sugar-sweetened beverages; TG: triglycerides; wk: week; wks: weeks; y: year

Table 46 Risk of bias for randomized controlled trials examining the relationship between dairy compared to carbohydrate or protein comparator^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (effect of assignment) | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of reported results | Overall risk of bias
Meyer, 2004^17^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Kurowska, 1997^14^ | SOME CONCERNS | LOW | SOME CONCERNS | NOT APPLICABLE | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Pei, 2017^29^ | LOW | NOT APPLICABLE | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Raziani, 2017^31^ | LOW | NOT APPLICABLE | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW
Maki, 2013^16^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Beavers, 2010^26^ | LOW | NOT APPLICABLE | LOW | NOT APPLICABLE | LOW | LOW | SOME CONCERNS | SOME CONCERNS
van Meijl, 2011^23^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Roy, 2019^22^ | LOW | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Crippa, 2018^9^ | LOW | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Brassard, 2017^6^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | SOME CONCERNS

Table 47 Risk of bias for observational studies examining the relationship between dairy compared to carbohydrate or protein comparator^a^

| Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Haring, 2014^38^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Keller, 2020^41^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

Table 48 Evidence examining the relationship between dairy consumption compared to meat consumption and risk of cardiovascular disease in adults^a^

Study and Participant Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Methodological Considerations
Haring, 2014^38^; PCS, United States, ARIC; Analytic N = 12,066; Participant characteristics:; - Age: ~53.8 (5.7)y; 45-64y; - Female: 56%; - Race and/or ethnicity: 77% White; 23% Black; - SEP: 79% High school graduates; - BMI 27.1 kg/m2; - Health Status: 29% HTN; Excluded participants with self-reported diabetes, fasting blood glucose ≥126 mg/dL, non-fasting blood glucose ≥200 mg/dL or use of diabetes medication, a history of myocardial infarction, stroke, heart failure, coronary bypass surgery, angioplasty or with missing data on covariates of interest.; Participants that reported implausible energy intake or incomplete dietary information were excluded Current smoker: ~26% | Exposure and Comparators:; Continuous (1 svg/d substitution); - High-fat dairy; - Low-fat dairy; - Fish/seafood; - Eggs; - Nuts; - Legumes; Exposure assessment method: FFQ at baseline and ~6y follow-up (cumulative average); Baseline intake of study foods: Median: 0.4 svg/d of high-fat dairy, 0.4 svg/d of low-fat dairy, 0.4 svg/d of processed meat, 0.5 svg/d of red meat, 0.3 svg/d of poultry; Outcome(s): CHD (definite or probable MI, or CHD death); Outcome assessment methods and timing: Adjudicated using information from study visits, yearly telephone follow-up calls, review of hospital discharge lists and medical charts, death certificates, next-of-kin interviews, and physician-completed questionnaires at 22 y follow-up | [underlined: CHD per 1 svg/d substitution, HR (95% CI)]; Low-fat dairy for high-fat dairy: 0.93 (0.84, 1.02); [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy; Fish/seafood for high-fat dairy: 0.94 (0.75, 1.19); Low-fat dairy; Fish/seafood for low-fat dairy: 1.02 (0.80, 1.28); [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy; Eggs for high-fat dairy: 0.89 (0.75, 1.06); Nuts for high-fat dairy: 0.90 (0.78, 1.03); Legumes for high-fat dairy: 0.93 (0.73, 1.19); Low-fat dairy; Eggs for low-fat dairy: 0.96 (0.81, 1.14); Nuts for low-fat dairy: 0.97 (0.84, 1.11); Legumes for low-fat dairy: 1.01 (0.79, 1.28); [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy for processed meat: 1.04 (0.90, 1.20); High-fat dairy for red meat: 0.91 (0.74, 1.12); High-fat dairy for poultry: 1.12 (0.90, 1.40); Low-fat dairy for processed meat: 0.96 (0.84, 1.11); Low-fat dairy for red meat: 0.84 (0.68, 1.05); Low-fat dairy for poultry: 1.04 (0.83, 1.30) | Key confounders accounted for: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (all the food items in the table, fiber intake), total energy intake; Key confounders NOT accounted for: None; Other covariates accounted for: Study center, systolic blood pressure, use of antihypertensive and/or lipid lowering medication, HDL, total cholesterol, carbohydrate intake, magnesium intake; Limitations: Only Black and White participants are included, so the findings are not entirely generalizable. No preregistered data analysis plan; Funding: NHLBI/NIH; German Research Foundation; University of Wurzburg
Bernstein, 2012^54^; PCS, United States, NHS, HPFS; Analytic N = 127,160; Participant characteristics:; - Age: NHS ~57y, 30-55y; HPFS ~62y, 40-75y; - Female: 66%; - Race and/or ethnicity: Mostly White; - SEP: 100% nurses, health professionals; - BMI ~26 kg/m2; - Health Status: ~33% high BP (HPFS & NHS); ~38% high cholesterol (HPFS), 35% high cholesterol (NHS). Without cancer, diabetes, or CVD; Excluded participants diagnosed with cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of percutaneous coronary intervention or coronary artery bypass grafting) at baseline; excessive missing data on FFQ; implausible energy intake | Exposure and Comparators:; - Dairy, whole-fat (whole milk, ice cream, hard cheese, full fat cheese, cream, sour cream, cream cheese, butter); - Dairy, low-fat (skim/low-fat milk, 1% and 2% milk, yogurt, cottage and ricotta cheeses, low-fat cheese, sherbet); - Red meat: unprocessed red meat (hamburger, beef, pork, and lamb), processed red meat (beef hot dog, processed meats such as bologna and salami, and bacon); Exposure assessment method: Validated FFQ at baseline and every 4y (cumulative average); Baseline intake of study foods: Median ~1 svg/d of red meat; Outcome(s): Stroke [ischemic (thrombotic, embolic, or unspecified non-hemorrhagic), hemorrhagic, or of unknown type]; Outcome assessment methods and timing: Medical records, autopsy report, death certificate, or report by next-of-kin at 22-26 y follow-up | [underlined: Stroke by 1 svg/d substitution, HR (95% CI)] Low-fat dairy for red meat: 0.89 (0.83, 0.95) Whole-fat dairy for red meat: 0.90 (0.84, 0.96) | Key confounders accounted for: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, fruit and vegetables, trans fat, other protein sources), total energy intake; Key confounders NOT accounted for: Socioeconomic position; Other covariates accounted for: time period, parental history of MI (<60y), menopausal status (women), multivitamin use, vitamin E supplement use, aspirin use; Limitations: Unclear how many participants were excluded for exposure missingness vs. previous diagnosis of a condition; No preregistered data analysis plan; Funding: NIH; Harvard Human Nutrition Program
Bernstein, 2010^34^; PCS, United States, NHS; Analytic N = 84,136; Participant characteristics:; - Age: ~58 y; 30-55y; - Female: 100%; - Race and/or ethnicity: White; - SEP: 100% Nurses, health professionals; - BMI ~26 kg/m2; - Health Status: 34% history of high BP; 36% history of high cholesterol; Excluded participants with incomplete FFQ; implausible TEI; previously diagnosed cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of coronary artery bypass grafting) | Exposure and Comparators:; Continuous (1 svg/d substitution); - Poultry (chicken with and without skin, chicken sandwich, and chicken/turkey hot dog); - Fish (canned tuna, dark- and light-fleshed fish, and breaded fish); - Red meat (hamburger, beef hot dog, processed meat, and processed meat sandwich, bacon, beef/pork/lamb as a mixed and main dish); - Dairy, high-fat (whole milk, ice cream, hard cheese, full-fat cheese, cream, sour cream, cream cheese, butter); - Dairy, low-fat (skim/low-fat milk, 1% and 2% milk, yogurt, cottage and ricotta cheeses, low-fat cheese, sherbert); Exposure assessment method: Validated FFQ at baseline and every 4y (cumulative average); Baseline intake of study foods: Median ~1.06 svg/d of red meat and ~0.14 svg/d of poultry; Outcome(s): CHD (nonfatal myocardial infarction and fatal CHD); Outcome assessment methods and timing: Medical records, state vital records, National Death Index, postal system or report by a kin at 26 y follow-up | [underlined: CHD by 1 svg/d substitution]; High-fat dairy for fish: Data NR (figure showing >1 HR), P<0.05; Low-fat dairy for fish: Data NR (figure only), P=NS; [underlined: CHD by 1 svg/d substitution, RR (95% CI)]; High-fat dairy for poultry: Data NR (figure only), P=NS; Low-fat dairy for poultry: Data NR (figure only), P=NS; High-fat dairy for red meat: Data NR (figure showing <1 HR), P<0.05; Low-fat dairy for red meat: 0.87 (0.81, 0.94) | Key confounders accounted for: Sex, age, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, trans fat), total energy intake, socioeconomic position; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: time period, menopausal status, parental history of early myocardial infarction, years of multivitamin use, vitamin E supplement use, aspirin use; Limitations: No preregistered data analysis plan; Funding: NIH; Unilever
Al-Shaar, 2020^53^; PCS, United States, HPFS; Analytic N = 43,272; Participant characteristics:; - Age: 53 (9.5) y; 40-75 y; - Female: 0%; - Race and/or ethnicity: 95% White; - SEP: All health professionals; - BMI 25.5 (3.3) kg/m2; - Health Status: 20% history of HTN, 10% high cholesterol; Excluded those with missing data; energy intake <800 or >4200 kcal/d; history of cancer, myocardial infarction, angina, CABG, or stroke | Exposure and Comparators:; Continuous (1 svg/d substitution); - High-fat dairy: whole milk; cream (e.g., coffee, sour excluding fat-free); regular ice cream; cottage or ricotta cheese; cream cheese; other regular cheese (e.g., American, cheddar, etc., plain or as part of a dish); - Low-fat dairy: skim milk, 1% milk, 2% milk; frozen yogurt, sherbet, sorbet or low-fat ice cream; plain yogurt; artificially-sweetened (e.g., light peach) yogurt; sweetened (e.g., strawberry, vanilla) yogurt; other lowfat or lite cheese (e.g., American, cheddar, etc., plain or as part of a dish); other fat-free cheese (e.g., American, cheddar, etc., plain or as part of a dish); - Cheese: cottage or ricotta cheese, cream cheese, and other cheese; - Total red meat: processed and unprocessed red meat; - Unprocessed red meat: hamburger (lean or extra lean), regular hamburgers, beef, pork, or lamb as a sandwich or main or mixed dish (e.g., stew, casserole, lasagna, frozen dinners, etc).; - Processed red meat: beef or pork hotdogs, bacon, salami, bologna, other processed meat sandwiches, other processed meats (e.g., sausages, kielbasa, etc); Exposure assessment method: Validated FFQ at baseline and every 4 years; Baseline intake of study foods: NR; Outcome(s): CHD (acute non-fatal MI or fatal CHD); Outcome assessment methods and timing: Physician review of medical records, telephone interview of supplemental information, death certificate at 30 y follow-up | [underlined: CHD by 1 svg/d substitution, HR (95% CI)]; High-fat dairy for total red meat: 0.88 (0.82, 0.94), P<0.001; High-fat dairy for unprocessed red meat: 0.89 (0.81, 0.97), P=0.01; High-fat dairy for processed red meat: 0.85 (0.78, 0.93), P<0.001; Low-fat dairy for total red meat: 0.89 (0.84, 0.95), P<0.001; Low-fat dairy for unprocessed red meat: 0.90 (0.82, 0.98), P=0.02; Low-fat dairy for processed red meat: 0.86 (0.79, 0.94), P<0.001; Whole milk for total red meat: 0.90 (0.82, 0.99), P=0.03; Whole milk for unprocessed red meat: 0.90 (0.81, 1.01), P=0.08; Whole milk for processed red meat: 0.86 (0.77, 0.97), P=0.010; Cheese for total red meat: 0.89 (0.82 to 0.98), P=0.01; Cheese for unprocessed red meat: 0.91 (0.81 to 1.01), P=0.07; Cheese for processed red meat: 0.86 (0.77 to 0.96), P=0.007 | Key confounders accounted for: Sex, age, race and/or ethnicity, socioeconomic position (marital status, living arrangement, profession, work status), physical activity, anthropometry, smoking, alcohol, diet quality (intakes of poultry, fish, egg, high fat dairy, low fat dairy, nuts, legumes, soy, whole grains, fruits, vegetables), TEI; Key confounders NOT accounted for: None; Other covariates accounted for: multivitamin and/or aspirin use; family history of CHD or stroke; intake of coffee; glycemic index; Limitations: No preregistered data analysis plan; Funding: NIH
Key, 2019^56^; PCS, 9 European countries, EPIC; Analytic N = 409,885; Participant characteristics:; - Age: 52.7 (10.3) y in men, 51.3 (9.8) y in women; - Female: 74%; - Race and/or ethnicity: NR; - SEP: 46% vocational or university education; - BMI 26.6 (3.7) kg/m2 in men, 25.0 (4.4) kg/m2 in women; - Health Status: ~3% with hx of DM, ~17% with previous HTN, ~19% with prior hyperlipidemia; Excluded those with missing data, top or bottom 1% of ratio of energy intake to energy requirement, MI or stroke | Exposure and Comparators:; Continuous (100 kcal/d substitution); - Red meat: unprocessed, including beef, veal, pork, lamb, mutton, goat, horse, hamburger, meatballs, minced meat; - Processed meat : meat products, including poultry, preserved by methods other than freezing, such as salting with or without nitrites, smoking, marinating, air drying, or heating, and including ham, bacon, sausages, blood sausages, chicken sausage, meat cuts, liver paté, salami, bologna, tinned meat, luncheon meat, corned beef and black pudding); - Cheese (data NR); Exposure assessment method: Validated FFQ at baseline on usual intake during previous year (country-specific); Baseline intake of study foods: NR; Outcome(s): Ischemic heart disease (IHD): composite of first non-fatal MI or death from IHD; Outcome assessment methods and timing: Hospital registries and self-reports confirmed with medical records; mortality registries or follow-up with next of kin at 12.6 y follow-up | [underlined: IHD by 100 kcal/d substitution, HR (95% CI)]; Cheese for red and processed meat: 0.85 (0.79, 0.92) | Key confounders accounted for: Sex, age, socioeconomic position (employment status, education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit and vegetable intake, sugar, fiber), TEI; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: History of DM, hypertension, hyperlipidemia, EPIC center, other foods as appropriate (poultry meat, white fish, fatty fish, milk, yogurt, cheese, and eggs); Limitations: Diet measured at baseline only; No preregistered data analysis plan; Some variations in the ascertainment and validation of the endpoint; Funding: UK Medical Research Council; Cancer Research UK; Wellcome Trust; European Union Framework 7; European Research Council; British Heart Foundation; UK National Institute of Health Research; European Commission; International Agency for Research on Cancer
van den Brandt, 2019^57^; Nested case control, The Netherlands, The Netherlands Cohort Study; Analytic N = 8823 deaths and 3202 subcohort members; Participant characteristics:; - Age: 61 y; 55-69 y; - Female: 60%; - Race and/or ethnicity: NR; - SEP: 16% university or higher vocational education; - BMI ~25 kg/m2; - Health Status: Generally healthy; HTN ~25%; ~3% T2D; Excluded those with a history of cancer (excluding skin cancer) or CVD (myocardial infarction, angina pectoris, stroke) at baseline, incomplete or inconsistent dietary data, or missing on confounders | Exposure and Comparators:; Continuous (50 g/d substitution); - Processed meat: meat items that have undergone some form of preservation (mostly treatment with nitrite salt, sometimes smoked or fermented); included ham, bacon, smoked beef or pork loin roll, and other slided cold meals (e.g., sausages); mainly referred to processed red meat, may contain small amounts of processed white meat (poultry) as in sausages; - Dairy, low-fat: include nonfermented and fermented low-fat milk and low-fat cheese; Exposure Assessment Method: Validated FFQ at baseline on usual consumption during previous year; Outcome(s): CVD mortality; Outcome assessment methods and timing: CVD mortality determined from linkage with the Dutch Central Bureau of Genealogy and Statistics Netherlands at 10 y follow-up | [underlined: CVD mortality by 50 g/d substitution, HR (95% CI)] Low-fat dairy for processed meat: 0.81 (0.66, 1.00) | Key confounders accounted for: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit and vegetable intake), TEI; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: HTN, diabetes, use of nutritional supplements; postmenopausal HRT in women; Limitations: Diet measured at baseline only; No preregistered data analysis plan; Funding: NR
Ibsen, 2022^55^; PCS, Sweden, Swedish; Mammography Cohort and Cohort of Swedish Men; Analytic N = 76,122; Participant characteristics:; - Age: 59 y (median); 45-83 y; - Female: 46%; - Race and/or ethnicity: NR; - SEP: 18% university education 47% with BMI 18.6-24.9 kg/m2; - Health Status: 21% HTN, 10% hypercholesterolemia; Excluded those with missing data, cancer, HF, ischemic heart disease; ±3 SD of mean TEI on log scale | Exposure and Comparators:; Substitution: 200g/d for low-fat dairy; - Red meat (meatballs, pork, veal, kidney and other organ meats) +; - Processed meat (sausage, black pudding, liver paste, ham); - Dairy, low-fat (0.5% milk, 1.5% milk, 0.5% sour milk yogurt, cottage cheese; not including low-fat cheese or light creme fraiche); Exposure assessment method: Validated FFQ at baseline (and some participants at 12y follow-up); Baseline intake of study foods: NR; Outcome(s): Heart failure; Outcome assessment methods and timing: Swedish Patient Register validated against medical records at 22 y (median) follow-up | [underlined: Heart failure risk by substitution, HR (95% CI)]; Low-fat dairy (200g/d) for red and processed meat (100g/d): 0.93 (0.90, 0.96) | Key confounders accounted for: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, nut/legumes, whole grains), TEI; Key confounders NOT accounted for: Race and/or ethnicity; Other covariates accounted for: Use of corticosteroids, aspirin, and/or dietary supplements; hormone replacement therapy (women); family history of myocardial infarction; history of HTN, hypercholesterolemia, diabetes, and/or atrial fibrillation; Limitations: Exposure measured at baseline only for unknown proportion of sample; No preregistered data analysis plan; Funding: Swedish Research Council; Swedish Research Council for Environment, Agricultural Sciences and Spatial Planning

Table 49 Risk of bias for observational studies examining dairy and dairy products consumption compared to meat consumption, and risk of cardiovascular disease in adults^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
van den Brandt, 2019^57^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Haring, 2014^38^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bernstein, 2012^54^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Bernstein, 2010^34^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Ibsen, 2022^55^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Al-Shaar, 2020^53^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Key, 2019^56^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH

Table 50 Evidence examining the relationship between red meat compared to plant sources of protein in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention/Exposure and Comparator | Results | Methodological Considerations
RANDOMIZED CONTROLLED TRIALS
Bergeron, 2019^58^; RCT-crossover, United States, APPROACH; (Animal and Plant Protein and Cardiovascular Health); Analytic N = 113; Adequately powered: No; Study aims: To test for differences in lipoprotein effects of diets in which the main source of protein is red meat compared with diets with similar total protein content derived from white meat (poultry) or plant protein sources, and to determine whether these effects were modified by high compared with low SFA intake.; Participant characteristics:; - Age: ~44 (12)y; 21-65y; - Female: 61%; - Race and/or ethnicity: 55% White, 20% Asian, 12% African American, 13% Other; - SEP: NR; - BMI: 26 (3.8) kg/m^2^; 42% with overweight, 16% with obesity; - Health Status: Majority normotensive; Excluded those using tobacco or recreational drugs; lipid-, glucose-, or blood-pressure-lowering medications, blood thinners, or hormones; unwillingness to consume all key study foods; weight loss >3% body weight in 3mo preceding study onset; history of coronary artery disease, diabetes, or other chronic disorder; BMI <20 or >35 kg/m^2^; blood pressure ≥150/90; fasting glucose ≥7 mmol/L, total and LDL cholesterol >95^th^% for sex and age; fasting triacylglycerol ≥5.65 mmol/L; unwillingness to refrain from use of vitamin supplements and alcoholic beverages during study | Intervention: Lean red meat: 11% energy from lean cuts of grain-finished beef and 1% energy from lean cuts of pork; Comparator: Non-meat sources of protein: legumes, nuts, grains, isoflavone-free soy products; 2-3% of energy from SFA was derived from tropical oils and fats with the remainder from high-fat dairy; Other Comparator: Lean white meat: 8% energy from chicken and 4% energy from turkey; Fish, seafood, and processed meats were excluded from all diets. For all diets, the remaining protein (~13% energy) was derived from eggs, dairy, and vegetable sources). Differences in SFA content between the high- and low-SFA arms were achieved primarily by using high-fat dairy products and butter, with only 2-3% energy from SFAs derived from lean red or white meat.; Duration: 4wk each (2-7wk washout) Compliance: Yes, using 24h urinary urea nitrogen and creatinine concentrations to monitor protein intake and weekly collection of menu checklists, grocery receipts, and reported deviations from dietary instructions; Outcome assessment methods and timing:; - LDL, HDL, TG, SBP, DBP; - Fasting blood collection and blood pressure at baseline and 4wk postbaseline | [underlined: LDL (mmol/L)], Mean difference (SE) at 4 wk; Red meat−Non-meat: 0.16 (0.03), P<0.0001; White meat−Non-meat: 0.16 (0.03), P<0.0001; [underlined: HDL (mmol/L)], Mean difference (SE) at 4wk; Red meat−Non-meat: 0.03 (0.01), P=0.007; White meat−Non-meat: 0.04 (0.01), P=0.001; [underlined: TG (mmol/L)], Mean difference (SE) at 4wk; Red meat−Non-meat: −0.03 (0.02), P=0.15; White meat−Non-meat: −0.03 (0.02), P=0.17; [underlined: SBP (mmHg)], Mean (SD) at 4 wk; Non-meat vs. white-meat vs. red meat, between groups: P=0.48; [underlined: DBP (mmHg)], Mean (SD) at 4 wk; Non-meat vs. white-meat vs. red meat, between groups: P=0.87 | Limitations:; - Not sufficiently powered; Funding:; NIH
OBSERVATIONAL STUDIES
Al-Shaar, 2020^53^; PCS, United States, HPFS; Analytic N = 43,272; Participant characteristics:; - Age: 53 (9.5)y; 40-75y; - Female: 0%; - Race and/or ethnicity: 95% White; “mostly non-Hispanic”; - SEP: All health professionals; - BMI: 25.5 (3.3) kg/m^2^; - Health Status: 20% history of HTN, 10% high cholesterol; Excluded those with missing data; energy intake <800 or >4200 kcal/d; history of cancer, myocardial infarction, angina, CABG, or stroke | Exposure: Total red meat: processed and unprocessed red meat; Unprocessed red meat: hamburger (lean or extra lean), regular hamburgers, beef, pork, or lamb as a sandwich or main or mixed dish (e.g., stew, casserole, lasagna, frozen dinners, etc).; Processed red meat: beef or pork hotdogs, bacon, salami, bologna, other processed meat sandwiches, other processed meats (e.g., sausages, kielbasa, etc); Comparator: Continuous (1 svg/d substitution; 2 svg/d substitution for soy); - Beans/Legumes: beans or lentils (baked, dried or soup); peas or lima beans (fresh, frozen, canned) or soup; - Nuts: peanuts, walnuts, other nuts, peanut butter; - Plant-based proteins: nuts, beans/legumes, and soy foods; - Soy: tofu, soy burger, soybeans, miso or other soy protein; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - CHD (acute non-fatal MI or fatal CHD) from physician review of medical records, telephone interview of supplemental information, death certificate; - 30y | [underlined: CHD] by 1 svg/d substitution, HR (95% CI); Total red meat; Nuts for total red meat: 0.89 (0.82, 0.96), P=0.002; Beans/Legumes for total red meat: 0.82 (0.70, 0.96), P=0.01; Soy for total red meat (2 svg/d substitution): 0.67 (0.48, 0.93), P=0.02; Plant-based proteins for total red meat: 0.86 (0.80, 0.93), P<0.001; Unprocessed red meat; Nuts for unprocessed red meat: 0.89 (0.81, 0.98), P=0.02; Beans/Legumes for unprocessed red meat: 0.83 (0.70, 0.99), P=0.03; Soy for unprocessed red meat (2 svg/d substitution): 0.66 (0.48, 0.92), P=0.01; Plant-based proteins for unprocessed red meat: 0.87 (0.79, 0.95), P=0.003; Processed red meat; Nuts for processed red meat: 0.85 (0.77, 0.94), P=0.001; Beans/Legumes for processed red meat: 0.80 (0.68, 0.95), P=0.009; Soy for processed red meat (2 svg/d substitution): 0.66 (0.47, 0.91), P=0.01; Plant-based proteins for processed red meat: 0.83 (0.76, 0.91), P<0.001 | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (marital status, living arrangement, profession, work status), physical activity, anthropometry, smoking, alcohol, diet quality (intakes of poultry, fish, egg, high fat dairy, low fat dairy, nuts, legumes, soy, whole grains, fruits, vegetables), total energy intake; - Other: multivitamin and/or aspirin use; family history of CHD or stroke; intake of coffee; glycemic index; Limitations:; - No preregistered data analysis plan; Funding:; NIH
Bernstein, 2010^34^; PCS, United States, NHS; Analytic N = 84,136; Participant characteristics:; - Age: ~58y; 30-55y; - Female: 100%; - Race and/or ethnicity: Mostly White; - SEP: All nurses/health professionals; - BMI: ~26 kg/m^2^; - Health Status: 34% history of high BP; 36%history of high cholesterol; Excluded participants with incomplete FFQ; implausible TEI; previously diagnosed cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of coronary artery bypass grafting) | Exposure: Red meat: hamburger, beef hot dog, processed meat, and processed meat sandwich, bacon, beef/pork/lamb as a mixed and main dish; Comparator: Continuous (1 svg/d substitution); - Nuts: including peanuts, walnuts, other nuts; - Beans: including lentils, baked or dry; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - CHD (nonfatal MI and fatal CHD) from medical records, state vital records, National Death Index, postal system or report by kin; - 26y | [underlined: CHD] by 1 svg/d substitution, RR (95% CI); Nuts for red meat: 0.70 (0.58, 0.83); Beans for red meat: Data NR (figure only), P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, trans fat), total energy intake; - Other: time period, menopausal status, parental history of early myocardial infarction, years of multivitamin use, vitamin E supplement use, aspirin use; Limitations:; - Did not account for key confounders: Socioeconomic position; - No preregistered data analysis plan; Funding:; NIH; Unilever
Bernstein, 2012^54^; PCS, United States, NHS, HPFS; Analytic N = 127,160; Participant characteristics:; - Age: NHS ~57y, 30-55y; HPFS ~62y, 40-75y; - Female: 66%; - Race and/or ethnicity: Mostly White; - SEP: All nurses/health professionals; - BMI: ~26 kg/m^2^; - Health Status: ~33% high BP (HPFS & NHS); ~38% high cholesterol (HPFS), 35% high cholesterol (NHS); Excluded participants diagnosed with cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of percutaneous coronary intervention or coronary artery bypass grafting) at baseline; excessive missing data on FFQ; implausible energy intake | Exposure: Red meat: unprocessed red meat (hamburger, beef, pork, and lamb), processed red meat (beef hot dog, processed meats such as bologna and salami, and bacon); Comparator: Continuous (1 svg/d substitution); - Legumes: dry beans, peas, soy, and tofu; - Nuts: including peanuts, walnuts, other nuts; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - Stroke [ischemic (thrombotic, embolic, or unspecified non-hemorrhagic), hemorrhagic, or of unknown type] from medical records, autopsy report, death certificate, or report by next-of-kin; - 22-26 y | [underlined: Stroke] by 1 svg/d substitution, HR (95% CI) Nuts for red meat: 0.87 (0.73, 0.96) Legumes for red meat: Data NR (figure only), P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, fruit and vegetables, trans fat, other protein sources), total energy intake; - Other: time period, parental history of MI (<60y), menopausal status (women), multivitamin use, vitamin E supplement use, aspirin use; Limitations:; - Did not account for key confounders: Socioeconomic position; - Unclear how many participants were excluded for exposure missingness vs. previous diagnosis of a condition; - No preregistered data analysis plan; Funding:; NIH; Harvard Human Nutrition Program
Haring, 2014^38^; PCS, United States, ARIC; Analytic N = 12,066; Participant characteristics:; - Age: ~53.8 (5.7)y; 45-64y; - Female: 56%; - Race and/or ethnicity: 77% White; 23% Black; - SEP: 79% high school graduates; - BMI: 27.1 kg/m^2^; - Health Status: 29% HTN; ~26% current smoker; Excluded participants with self-reported diabetes, fasting blood glucose ≥126 mg/dL, non-fasting blood glucose ≥200 mg/dL or use of diabetes medication, a history of myocardial infarction, stroke, heart failure, coronary bypass surgery, angioplasty or with missing data on covariates of interest, implausible energy intake or incomplete dietary information | Exposure: Processed red meat: details NR Red meat: unprocessed, details NR; Comparator: Continuous (1 svg/d substitution); - Nuts: details NR; - Legumes: details NR; Assessment methods and timing:; - FFQ at baseline and ~6y follow-up (cumulative average); Outcome assessment methods and timing:; - CHD (definite or probable MI, or CHD death) adjudicated using information from study visits, yearly telephone follow-up calls, review of hospital discharge lists and medical charts, death certificates, next-of-kin interviews, and physician-completed questionnaires; - 22y | [underlined: CHD] by 1 svg/d substitution, HR (95% CI) Nuts for processed meat: 0.94 (0.79, 1.10) Legumes for processed meat: 0.97 (0.74, 1.27); Nuts for red meat: 0.81 (0.65, 1.02); Legumes for red meat: 0.85 (0.61, 1.18) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (all the food items in the table, fiber intake), total energy intake; - Other: study center, systolic blood pressure, use of antihypertensive and/or lipid lowering medication, HDL, total cholesterol, carbohydrate intake, magnesium intake; Limitations:; - No preregistered data analysis plan; Funding:; NHLBI/NIH; German Research Foundation; University of Wurzburg
Ibsen, 2022^55^; PCS, Sweden, Swedish Mammography Cohort and Cohort of Swedish Men; Analytic N = 76,122; Participant characteristics:; - Age: 59y; 45-83y; - Female: 46%; - Race and/or ethnicity: NR; - SEP: 18% university education; - BMI: 47% with 18.6-24.9 kg/m^2^; - Health Status: 21% HTN, 10% hypercholesterolemia; Excluded those with missing data, cancer, HF, ischemic heart disease; ±3 SD of mean TEI on log scale | Exposure: Red meat (meatballs, pork, veal, kidney and other organ meats) and processed meat (sausage, black pudding, liver paste, ham) combined; Comparator: Continuous (20 g/d for nuts and legumes); - Nuts and legumes: peas, pea soup, soya, nuts; Assessment methods and timing:; - FFQ at baseline (and some participants at 12y follow-up); Outcome assessment methods and timing:; - Heart failure from Swedish Patient Register validated against medical records; - 22y (median) | [underlined: Heart failure] by 20 g/d substitution, HR (95% CI); Nuts and legumes for red and processed meat: 0.92 (0.89, 0.95) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, nut/legumes, whole grains), total energy intake; - Other: use of corticosteroids, aspirin, and/or dietary supplements; hormone replacement therapy (women); family history of myocardial infarction; history of HTN, hypercholesterolemia, diabetes, and/or atrial fibrillation; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only for unknown proportion of sample; - No preregistered data analysis plan; Funding:; Swedish Research Council; Swedish Research Council for Environment, Agricultural Sciences and Spatial Planning
Razavi, 2020^74^; PCS, United States, Bogalusa Heart Study; Analytic N = 456; Participant characteristics:; - Age: 36.1 (4.4)y; 24-44y; - Female: 63%; - Race and/or ethnicity: 73% White; 27% Black; - SEP: 45% with post-high school education; - BMI: 28.7 (6.8) kg/m^2^; - Health Status: LDL 122.7 (31.7) mg/dL; HDL 48.3 (13.4) mg/dL; Excluded those with missing data; dietary intake of <500 or >5000 kcal/d; those on blood pressure, lipid, and/or glucose-lowering therapy | Exposure: Red meat: whole beef, pork, meatballs, liver; Processed meat: hamburger meat, chicken nuggets, hot dogs, and deli meat, including turkey, roast beef, bologna, and salami; Comparator: Continuous (1 svg/wk isocaloric substitution); - Legumes: beans, lentils, soybeans, string beans, and tofu; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Left ventricular diastolic dysfunction (LVDD) from echocardiographic measurement; - 12.9y | [underlined: Risk of LVDD] by 1 svg/wk isocaloric substitution, OR (95% CI); Legumes for red meat: 0.78 (0.62, 0.98); Legumes for processed meat: data NR (figure only), P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), anthropometry, smoking, alcohol, total energy intake; - Other: TG, LDL, HDL, SBP, DBP, fasting blood glucose, eGFR; Limitations:; - Did not account for key confounders: Physical activity, diet quality; - Exposure measured at baseline only; - No preregistered data analysis plan; Funding:; NIH
Sun, 2021^80^; PCS, United States, Women’s Health Initiative; Analytic N = 102,521; Participant characteristics:; - Age: 62 (7)y; 50-79y; - Female: 100%; - Race and/or ethnicity: 82% White; 9% Black; ~4% Hispanic; ~5% Other/Missing; - SEP: 32% high school or less, 27% some college, 40% college or higher; 37% annual income >$50K; - BMI: ~27 (5) kg/m^2^; - Health Status: 48% family history of heart attack; 36% family history of stroke; Excluded those with missing data, energy intake <600 or >5000 kcal/d, CVD or cancer at baseline | Exposure: Total red meat: unprocessed (beef, pork, veal, lamb, and game) and processed (franks, sausages, luncheon meats); Poultry: chicken, turkey, and other poultry Total red meat and poultry were computed into ounce equivalent according to protein content (1 oz meat = 1 oz equivalent of protein food); Comparator: Continuous (2 oz-eq/d substitution); - Legumes: soy products, beans, and peas; computed into ounce equivalent according to protein content (1/4 cup beans = 1 oz equivalent of protein food); - Nuts: nuts and seeds; computed into ounce equivalent according to protein content (0.5 oz nuts = 1 oz equivalent of protein food); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD mortality (included deaths from atherosclerotic cardiac, definite coronary heart disease, possible coronary heart disease, cerebrovascular disease, pulmonary embolism, and other or unknown cardiovascular disease) from death certificates, medical records, autopsy reports, or linkage to National Death Index; - 18.1y | [underlined: CVD mortality] by 2 oz-eq/d substitution, HR (95% CI); Nuts for total red meat: data NR (figure only), P=NS; Nuts for poultry: data NR (figure only), P=NS; Legumes for total red meat: data NR (figure only), P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education, income), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, whole grains, SSB, and other protein sources), total energy intake; - Other: hormone use; family history of heart attack/stroke; Limitations:; - Exposure measured at baseline only; - Data not provided beyond figure; - No preregistered data analysis plan; Funding:; NHLBI
Thao, 2023^81^; PCS, France, E3N; Analytic N = 45,771; Participant characteristics:; - Age: 51.8 (6.3)y; 40-65y; - Female: 100%; - Race and/or ethnicity: NR; - SEP: 36% university education; - BMI: 22.9 (3.2) kg/m^2^; - Health Status: 6% history of CVD; Excluded those with HTN, CVD, stroke, or myocardial infarction; missing dietary data or reporting no meat/fish intake; <1000 or >4000 kcal/d | Exposure: Processed red meat: sausage, ham, charcuterie, and pâté; Comparator: Continuous (150 g/wk substitution); - Pulses: details NR; Assessment methods and timing:; - FFQ at baseline and 12y follow-up (only baseline used in main analysis; follow-up used in sensitivity analyses); Outcome assessment methods and timing:; - HTN from self-report of date of diagnosis and use of antihypertensive treatments; validated with medication reimbursement; - 18.3y | [underlined: Incident HTN] by 150 g/wk substitution, HR (95% CI); Pulses for processed red meat: 0. 97 (0.95, 0.99); Data also provided stratified by BMI, smoking status, and history of diabetes; Secondary analysis also conducted using second FFQ | Model adjustments:; - Key confounders: Sex, age (at menopause), socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (SSB intake), total energy intake; - Other: family history of CVD and prevalent diabetes; use of menopausal hormone therapy; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - No preregistered data analysis plan; Funding:; Mutuelle Générale de l’Education Nationale; European Community; French League against Cancer; Gustave Roussy Institute; French Institute of Health and Medical Research; French Research Agency
van den Brandt, 2019^57^; NCC, The Netherlands, The Netherlands Cohort Study; Analytic N = 8823 deaths and 3202 subcohort members; Participant characteristics:; - Age: 61y; 55-69y; - Female: 60%; - Race and/or ethnicity: NR; - SEP: 16% university or higher vocational education; - BMI: ~25 kg/m^2^; - Health Status: ~25% HTN; ~3% T2D; Excluded those with a history of cancer (excluding skin cancer) or CVD (myocardial infarction, angina pectoris, stroke) at baseline, incomplete or inconsistent dietary data, or missing on confounders | Exposure: Processed meat: meat items that have undergone some form of preservation (mostly treatment with nitrite salt, sometimes smoked or fermented); included ham, bacon, smoked beef or pork loin roll, and other slided cold meals (e.g., sausages); mainly referred to processed red meat, may contain small amounts of processed white meat (poultry) as in sausages; Comparator: Continuous (50 g/d substitution); - Nuts: details NR; - Pulses: details NR; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD mortality determined from linkage with the Dutch Central Bureau of Genealogy and Statistics Netherlands; - 10y | [underlined: CVD mortality] by 50 g/d substitution, HR (95% CI); Nuts for processed meat: 0.62 (0.44, 0.88); Pulses for processed meat: 0.82 (0.58, 1.15) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit and vegetable intake), total energy intake; - Other: diabetes, HTN, use of nutritional supplements; postmenopausal HRT in women; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only; - No preregistered data analysis plan; Funding:; NR
Wang, 2024^83^; PCS, United States, Million Veteran Program; Analytic N = 148,506; Participant characteristics:; - Age: 61y; - Female: 12%; - Race and/or ethnicity: 81% White; 13% African American; 7% Hispanic; 1% Asian; 1% American Indian; 3% Other; - SEP: 50% college or above; 58% married; 33% family income ≥$60K/y; - BMI: ~28 kg/m^2^; - Health Status: 38% HTN; 35% hypercholesterolemia; Excluded those with missing data, diabetes, cancer, CVD, energy intake <400 or ≥4000 kcal/d (women) or <450 or ≥4500 kcal/d (men) | Exposure: Red meat: unprocessed and processed red meat; Unprocessed red meat: beef, pork, and lamb as a main dish, sandwich, or mixed dish (3oz svg); hamburger patty; Processed red meat: bacon, hot dogs, sausage, salami, bologna, and other processed red meats; Comparator: Continuous (0.5 svg/d substitution); - Nuts: details NR; - Beans/legumes: details NR; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and nonfatal, including myocardial infarction and acute ischemic stroke) from National Death Index and validated high-throughput phenotyping algorithm; - 3.8y | [underlined: Incident CVD] by 0.5 svg/d substitution, RR (95% CI); Nuts for total red meat: 0.84 (0.83, 0.90); Nuts for unprocessed red meat: Reduced risk (data NR, figure only), P<0.05; Nuts for processed red meat: Reduced risk (data NR, figure only), P<0.05; Beans/legumes for total red meat: 0.97 (0.92, 1.01); Beans/legumes for unprocessed red meat: P=NS; Beans/legumes for processed red meat: P = NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education, income, marriage status), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, nuts, yogurt, whole grain, legume, skim milk, eggs, nonskin chicken, fish, SSB), total energy intake; - Other: history of HTN or hypercholesterolemia; Limitations:; - Exposure measured at baseline only; - Inadequate adjustment for missing data; - No preregistered data analysis plan; Funding:; U.S. Department of Veterans Affairs
Zhong, 2021^87^; PCS, United States, Multiple cohorts (ARIC, CARDIA, CHS, FHS, FOS, MESA); Analytic N = 29,682; Participant characteristics:; - Age: 53.7 (15.7)y; - Female: 56%; - Race and/or ethnicity: 69% non-Hispanic White; 24% non-Hispanic Black; 4.5% Hispanic; 2% Chinese; <1% Other; - SEP: 53% some college or more; 47% high school or less; - BMI: NR; - Health Status: Generally healthy; Excluded those with CVD at baseline, missing data, or <500 or >6000 kcal/d | Exposure: Processed meat: 1 svg equivalent to two slices of bacon, two small links of sausage or one hot dog; Unprocessed red meat: details NR; 1 svg equivalent to 85.05 g (i.e., 3 oz); Comparator: Continuous (1 svg/wk substitution); - Nuts: including seeds and nut butter; 1 svg equivalent to 28.35 grams (i.e., 1 oz) of nuts or seeds, one tablespoon of nut butter; - Legumes: details NR; 1 svg equivalent to 1/2 cup legumes; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and non-fatal CHD, fatal and non-fatal stroke, fatal and non-fatal heart failure, and other CVD deaths) from medical records and/or autopsy data; - 19y | [underlined: Incident CVD] by 1 svg/wk substitution, HR (95% CI); Nuts for processed meat: 0.95 (0.93, 0.98), P<0.01; Nuts for unprocessed red meat: 0.98 (0.97, 0.99), P<0.01; Legumes for processed meat: 0.96 (0.93, 0.98), P<0.01; Legumes for unprocessed read meat: 0.99 (0.97, 1.00); Results also provided for 1 svg/d substitution, as well as absolute risk difference. | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, smoking, alcohol, diet quality (AHEI), total energy intake; - Other: cohort; other foods (eggs, processed meat, unprocessed red meat, poultry, fish, nuts, legumes, whole grains); hormone therapy; Limitations:; - Did not account for key confounders: Anthropometry; - Exposure measured at baseline only; - Inadequate information on amount of missingness; - No preregistered data analysis plan; Funding:; AHA Strategically Focused Research Network; NHLBI; Northwestern University Feinberg School of Medicine
Zhu, 2022^88^; PCS, Multiple (Finland, UK, New Zealand, Australia), Secondary analysis of PREVIEW trial; Analytic N = 668; Participant characteristics:; - Age: 57y; 26-70y; - Female: 69%; - Race and/or ethnicity: 86% Caucasian; 3% Black; 3% Asian; 7% Other; 1% Arabic; - SEP: NR; - BMI: 29.5 kg/m^2^; - Health Status: 100% prediabetes; Excluded those <25 or >70y; BMI <25 kg/m^2^; without prediabetes based on ADA 2022 criteria; type 1 or type 2 diabetes; missing dietary data; <600 or >3500 kcal/d for women, or <800 or >4200 kcal/day for men | Exposure: Processed meat: frankfurters, sausage, bacon, corned beef, cured ham and luncheon meat made from beef, pork, poultry; Comparator: Continuous (60-72 kcal/d substitution); - Legumes: pulses, beans, peas, lentils, soy foods; - Nuts: nuts and seeds; Assessment methods and timing:; - 4d diet records at 25, 52, 104, and 156wk (cumulative average); Outcome assessment methods and timing:; - TG from fasting blood collection at 8, 26, 52, 104, and 156wk; - 3y | [underlined: TG (mmol/L)] by 60-72 kcal/d substitution, Mean change per year (95% CI); Nuts for processed meat: −0.03 (−0.06, 0.003), P=0.074; Legumes for processed meat: −0.03 (−0.07, 0.01), P=0.176 | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, alcohol, diet quality (intake of animal-based food, grains, legumes, nuts, fruit, vegetables, and sugar), total energy intake; - Other: intervention center, yearly weight change; Limitations:; - Did not account for key confounders: Socioeconomic position, smoking; - No preregistered data analysis plan; Funding:; EU framework programme 7; National Health and Medical Research Council; The Glycemic Index Foundation Australia; The New Zealand Health Research Council; University of Auckland Faculty Research Development Fund; Danish Agriculture & Food Council; Danish Meat and Research Institute; National Institute for Health Research Biomedical Research Centre; Engineering and Physical Sciences Research Council

Table 51 Risk of bias for randomized controlled trial examining red meat compared to plant sources of protein in adults and older adults and risk of cardiovascular disease^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bergeron, 2019^58^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 52 Risk of bias for observational studies examining red meat compared to plant sources of protein in adults and older adults and risk of cardiovascular disease^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Al-Shaar, 2020^53^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bernstein, 2010^34^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bernstein, 2012^54^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Haring, 2014^38^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Ibsen, 2022^55^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Razavi, 2020^74^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Sun, 2021^80^ | LOW* | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Thao, 2023^81^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
van den Brandt, 2019^57^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Wang, 2024^83^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Zhong, 2021^87^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zhu, 2022^88^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 53 Evidence examining the relationship between red meat compared to fruit and vegetables in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention/Exposure and Comparator | Results | Methodological Considerations
RANDOMIZED CONTROLLED TRIALS
Poddar, 2013^73^; RCT-parallel, United States; Analytic N = 73; Adequately powered: NR; Study aims: Primary: To assess weight loss and weight maintenance efficacy with white button mushrooms as a substitute for red meat over 1 year; Secondary: to assess health parameters on the mushroom vs. meat diet, including blood pressure, lipid profile, and biochemical indicators of inflammation and oxidative stress; Participant characteristics:; - Age: 48.4 (1.4)y; 18-65y; - Female: 88%; - Race and/or ethnicity: 45% White/Caucasian; 53% African American; 2% Hispanic; - SEP: NR; - BMI: all 25-40 kg/m^2^ (inclusion criteria); - Health Status: No uncontrolled chronic health conditions (inclusion criteria); Excluded BMI <25 or >40 kg/m^2^; history of HIV, carcinoma, rheumatoid arthritis, or other uncontrolled chronic health condition; regular use of medications and/or supplements that could affect weight; pregnant or nursing | Intervention: Red meat/Control: ≥90% lean ground beef at 3 meals each week; participants were prescribed a 500 kcal/d energy-deficit diet in first 6mo and received dietary instruction without the recommendation of mushroom substitution; Comparator: Mushroom: substituted white button mushrooms (8oz) for red meat at 3 meals each week by incorporating in sauteed vegetables, “burgers”, and other normally meat-containing dishes; participants were prescribed a 500 kcal/d energy-deficit diet in first 6mo and received dietary instruction on preparing and using mushroom substitutes for meat; Duration: 12mo (6mo weight loss, 6mo weight maintenance); Compliance: No, non-compliance based on <32oz consumption of mushrooms in 2wk; 55% were non-compliant at 0-6mo; 39% non-compliant at 6-12mo; Outcome assessment methods and timing:; - LDL, SBP, DBP; - Fasting blood collection and blood pressure at baseline, 3mo, 6mo, and 12mo | [underlined: LDL (mg/dL)], Mean (SEM); Within group: baseline; ∆0-6mo; ∆6-12mo; Mushroom (N=36): 111 (5.50); −1.22 (3.08); −6.68 (5.54); Meat (N=37): 101 (5.56); 1.33 (3.94); −4.97 (4.99); Between group:; ∆0-6mo: P=0.611; ∆6-12mo: P=0.820; [underlined: SBP (mmHg)]; Within group: Mean at baseline; Mean (SEM) at ∆06mo; Mushroom (N=14): 132.9; −5.92 (2.98); Meat (N=25): 125.3; 5.52 (5.48); Between group: ∆0-6mo: P=0.150; [underlined: DBP (mmHg)]; Within group: Mean at baseline; Mean (SEM) at ∆06mo; Mushroom (N=14): 86.7; −3.71 (2.41); Meat (N=25): 87.2; −1.84 (2.35); Between group: ∆0-6mo: P=0.610 | Limitations:; - Insufficient information on randomization and allocation procedures; - High attrition; - Differences in compliance; - No power calculation; - No preregistered data analysis plan; Funding:; Mushroom Council; Australian; Mushroom Growers; Association
Ibsen, 2022^55^; PCS, Sweden, Swedish Mammography Cohort and Cohort of Swedish Men; Analytic N = 76,122; Participant characteristics:; - Age: 59y; 45-83y; - Female: 46%; - Race and/or ethnicity: NR; - SEP: 18% university education; - BMI: 47% with 18.6-24.9 kg/m^2^; - Health Status: 21% HTN, 10% hypercholesterolemia; Excluded those with missing data, cancer, HF, ischemic heart disease; ±3 SD of mean TEI on log scale | Exposure: Red meat (meatballs, pork, veal, kidney and other organ meats) and processed meat (sausage, black pudding, liver paste, ham) combined; Comparator: Continuous (100 g/d substitution); - Fruits: orange, apple, banana, berries, other fruits; - Vegetables: carrot, beetroot, lettuce, cabbage, cauliflower, broccoli, tomato, pepper, spinach, onion, garlic, other vegetables but not including potatoes; Assessment methods and timing:; - FFQ at baseline (and some participants at 12y follow-up); Outcome assessment methods and timing:; - Heart failure from Swedish Patient Register validated against medical records; - 22y (median) | [underlined: Heart failure] by 100 g/d substitution, HR (95% CI) Fruits for red and processed meat: 0.9 (0.87, 0.93) Vegetables for red and processed meat: 0.92 (0.88, 0.96) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, nut/legumes, whole grains), total energy intake; - Other: use of corticosteroids, aspirin, and/or dietary supplements; hormone replacement therapy (women); family history of myocardial infarction; history of HTN, hypercholesterolemia, diabetes, and/or atrial fibrillation; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only for unknown proportion of sample; - No preregistered data analysis plan; Funding:; Swedish Research Council; Swedish Research Council for Environment, Agricultural Sciences and Spatial Planning
Razavi, 2020^74^; PCS, United States, Bogalusa Heart Study; Analytic N = 456; Participant characteristics:; - Age: 36.1 (4.4)y; 24-44y; - Female: 63%; - Race and/or ethnicity: 73% White; 27% Black; - SEP: 45% with post-high school education; - BMI: 28.7 (6.8) kg/m^2^; - Health Status: LDL 122.7 (31.7) mg/dL; HDL 48.3 (13.4) mg/dL; Excluded those with missing data; dietary intake of <500 or >5000 kcal/d; those on blood pressure, lipid, and/or glucoselowering therapy | Exposure: Red meat: whole beef, pork, meatballs, liver; Processed meat: hamburger meat, chicken nuggets, hot dogs, and deli meat, including turkey, roast beef, bologna, and salami; Comparator: Continuous (1 svg/wk isocaloric substitution); - Fresh vegetables: tomatoes, broccoli, beets, corn, peas, mixed vegetables, spinach, kale, peppers, yams, zucchini, carrots, celery, and lettuce; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Left ventricular diastolic dysfunction (LVDD) from echocardiographic measurement; - 12.9y | [underlined: Risk of LVDD] by 1 svg/wk isocaloric substitution, OR (95% CI); Fresh vegetables for red meat: data NR (figure only), P=NS; Fresh vegetables for processed meat: data NR (figure only), P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), anthropometry, smoking, alcohol, total energy intake; - Other: TG, LDL, HDL, SBP, DBP, fasting blood glucose, eGFR; Limitations:; - Did not account for key confounders: Physical activity, diet quality; - Exposure measured at baseline only; - No preregistered data analysis plan; Funding:; NIH
Thao, 2023^81^; PCS, France, E3N; Analytic N = 45,771; Participant characteristics:; - Age: 51.8 (6.3)y; 40-65y; - Female: 100%; - Race and/or ethnicity: NR; - SEP: 36% university education; - BMI: 22.9 (3.2) kg/m^2^; - Health Status: 6% history of CVD; Excluded those with HTN, CVD, stroke, or myocardial infarction; missing dietary data or reporting no meat/fish intake; <1000 or >4000 kcal/d | Exposure: Processed red meat: sausage, ham, charcuterie, and pâté; Comparator: Continuous (150 g/wk substitution); - Vegetables: leafy and root vegetables (excluding potatoes and pulses); Assessment methods and timing:; - FFQ at baseline and 12y follow-up (only baseline used in main analysis; follow-up used in sensitivity analyses); Outcome assessment methods and timing:; - HTN from self-report of date of diagnosis and use of antihypertensive treatments; validated with medication reimbursement; - 18.3y | [underlined: Incident HTN] by 150 g/wk substitution, HR (95% CI) Vegetables for processed red meat: 0.96 (0.94, 0.98); Data also provided stratified by BMI, smoking status, and history of diabetes; Secondary analysis also conducted using second FFQ | Model adjustments:; - Key confounders: Sex, age (at menopause), socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (SSB intake), total energy intake; - Other: family history of CVD and prevalent diabetes; use of menopausal hormone therapy; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - No preregistered data analysis plan; Funding:; Mutuelle Générale de l’Education Nationale; European Community; French League against Cancer; Gustave Roussy Institute; French Institute of Health and Medical Research; French Research Agency
Wang, 2024^83^; PCS, United States, Million Veteran Program; Analytic N = 148,506; Participant characteristics:; - Age: 61y; - Female: 12%; - Race and/or ethnicity: 81% White; 13% African American; 7% Hispanic; 1% Asian; 1% American Indian; 3% Other; - SEP: 50% college or above; 58% married; 33% family income ≥$60K/y; - BMI: ~28 kg/m^2^; - Health Status: 38% HTN; 35% hypercholesterolemia; Excluded those with missing data, diabetes, cancer, CVD, energy intake <400 or ≥4000 kcal/d (women) or <450 or ≥4500 kcal/d (men) | Exposure: Red meat: unprocessed and processed red meat Unprocessed red meat: beef, pork, and lamb as a main dish, sandwich, or mixed dish (3oz svg); hamburger patty Processed red meat: bacon, hot dogs, sausage, salami, bologna, and other processed red meats; Comparator: Continuous (0.5 svg/d substitution); - Vegetables: details NR; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and nonfatal, including myocardial infarction and acute ischemic stroke) from National Death Index and validated high-throughput phenotyping algorithm; - 3.8y | [underlined: Incident CVD] by 0.5 svg/d substitution, RR (95% CI) Vegetables for total red meat: 0.97 (0.93, 0.98) Vegetables for unprocessed red meat: Reduced risk (data NR, figure only), P<0.05; Vegetables for processed red meat: Reduced risk (data NR, figure only)P<0.05 | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education, income, marriage status), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, nuts, yogurt, whole grain, legume, skim milk, eggs, nonskin chicken, fish, SSB), total energy intake; - Other: history of HTN or hypercholesterolemia; Limitations:; - Exposure measured at baseline only; - Inadequate adjustment for missing data; - No preregistered data analysis plan; Funding:; U.S. Department of Veterans Affairs
Würtz, 2016a^85^; PCS, Denmark, Danish Diet, Cancer and Health; Analytic N = 55,171; Participant characteristics:; - Age: 56y; 50-64y; - Female: 53%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: ~26 (21-33) kg/m^2^; - Health Status: 16% HTN, 7% hypercholesterolemia; Excluded those with previous diagnosis of cancer or MI, missing data | Exposure: Red meat: processed and unprocessed red meat Unprocessed red meat: included fresh and minced beef, veal, pork and lamb Processed red meat: included red meat items that had undergone processing such as smoking, salting or curing, which included various kinds of sausage, salami, smoked or cooked ham, other cold cuts, bacon and liver pate; Comparator: Continuous (150 g/wk substitution); - Vegetables: including fruiting vegetables (cucumber, aubergine, green pepper, red pepper, tomato, zucchini, avocado, green beans, green peas, maize), leafy vegetables (spinach, lettuce), root vegetables (carrot, celeriac, ginger), cabbage (cauliflower, broccoli, red cabbage, white cabbage, kale, Brussels sprouts), mushrooms (champignon, chanterelle), onion (onion, garlic) and stalk vegetables/sprouts (leek, bean sprouts, chives, asparagus, bamboo shoots, rhubarb); also included a few mixed dishes such as salad and vegetable patties, and vegetable content from standard recipes such as stew contributed small amounts Potatoes: including boiled, baked, roasted, fried and mashed potatoes (not including potato chips); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Myocardial infarction (non-fatal and fatal) from national registries, medical records; - 13.5y | [underlined: MI] by 150 g/wk substitution, HR (95% CI); Women; Total vegetables for total red meat: 0.94 (0.89, 0.99); Total vegetables for unprocessed red meat: 0.92 (0.86, 0.99); Total vegetables for processed red meat: 0.98 (0.88, 1.09); Potatoes for total red meat: 0.93 (0.88, 0.98); Potatoes for unprocessed red meat: 0.91 (0.85, 0.98); Potatoes for processed red meat: 0.97 (0.87, 1.08); Men; Total vegetables for total red meat: 0.97 (0.94, 1.00); Total vegetables for unprocessed red meat: 0.99 (0.95, 1.02); Total vegetables for processed red meat: 0.94 (0.90, 0.98); Potatoes for total red meat: 0.97 (0.95, 1.00); Potatoes for unprocessed red meat: 0.99 (0.96, 1.02); Potatoes for processed red meat: 0.94 (0.91, 0.98); Results also provided by 250 kcal/wk substitutions | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit, sweets, lean dairy products, fatty dairy products, potato chips, refined cereals, whole grain cereals, nuts), total energy intake; - Other: menopausal status and use of hormone replacement therapy (women); Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only; - No preregistered data analysis plan; Funding:; Danish Council for Strategic Research; Aarhus University; Danish Cancer Society

a Abbreviations: AHEI: Alternative Healthy Eating Index; BMI: body mass index; CABG: coronary artery bypass grafting; CHD: coronary heart disease; CHO: carbohydrate; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DBP: diastolic blood pressure; dL: deciliter(s); DM: diabetes mellitus; eq: equivalent; FFQ: food frequency questionnaire; HDL: high-density lipoprotein cholesterol; HTN: hypertension; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); m: meter(s); L: liter(s); LDL: low-density lipoprotein cholesterol; MI: myocardial infarction; mmHg: millimetre of mercury; mmol: millimole(s); mo: month(s); MUFA: monounsaturated fatty acids; NCC: nested case control; NR: not reported; NS: not significant; OR: odds ratio; oz: ounce(s); P: p-value; PCS: prospective cohort study; PUFA: polyunsaturated fatty acids; RCT: randomized controlled trial; RR: risk ratio; SBP: systolic blood pressure; SD: standard deviation; SEM: standard error of the mean; SFA: saturated fatty acids; SEP: socioeconomic position; SSB: sugar-sweetened beverages; svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; TG: triglycerides; wk: week(s); y: year(s)

Table 54 Risk of bias for randomized controlled trial examining red meat compared to fruit and vegetables in adults and older adults and risk of cardiovascular disease^a^

Article | Randomization | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Poddar, 2013^73^ | SOME CONCERNS | HIGH | SOME CONCERNS | LOW | HIGH | HIGH

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 55 Risk of bias for observational studies examining red meat compared to fruit and vegetables in adults and older adults and risk of cardiovascular disease^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Ibsen, 2022^55^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Razavi, 2020^74^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Thao, 2023^81^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Wang, 2024^83^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Würtz, 2016a^85^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 56 Evidence examining the relationship between red meat compared to whole grains and cereals in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention/Exposure and Comparator | Results | Methodological Considerations
Al-Shaar, 2020^53^; PCS, United States, HPFS; Analytic N = 43,272; Participant characteristics:; - Age: 53 (9.5)y; 40-75y; - Female: 0%; - Race and/or ethnicity: 95% White; “mostly non-Hispanic”; - SEP: All health professionals; - BMI: 25.5 (3.3) kg/m^2^; - Health Status: 20% history of HTN, 10% high cholesterol; Excluded those with missing data; energy intake <800 or >4200 kcal/d; history of cancer, myocardial infarction, angina, CABG, or stroke | Exposure: Total red meat: processed and unprocessed red meat; Unprocessed red meat: hamburger (lean or extra lean), regular hamburgers, beef, pork, or lamb as a sandwich or main or mixed dish (e.g., stew, casserole, lasagna, frozen dinners, etc).; Processed red meat: beef or pork hotdogs, bacon, salami, bologna, other processed meat sandwiches, other processed meats (e.g., sausages, kielbasa, etc); Comparator: Continuous (1 svg/d substitution); - Whole grains: whole grain breakfast cereal, other cooked breakfast cereal, cooked oatmeal, dark bread, rye/pumpernickle bread, crispbreads (e.g., Wasa), brown rice, other grains (e.g., bulgar, kasha, couscous, etc), oat bran or other bran (added to food), wheat germ, regular popcorn, fat-free/light popcorn, tortillas; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - CHD (acute non-fatal MI or fatal CHD) from physician review of medical records, telephone interview of supplemental information, death certificate; - 30y | [underlined: CHD] by 1 svg/d substitution, HR (95% CI); Whole grains for total red meat: 0.62 (0.53, 0.73), P<0.001; Whole grains for unprocessed red meat: 0.61 (0.51, 0.72), P<0.001; Whole grains for processed red meat: 0.59 (0.49, 0.69), P<0.001 | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (marital status, living arrangement, profession, work status), physical activity, anthropometry, smoking, alcohol, diet quality (intakes of poultry, fish, egg, high fat dairy, low fat dairy, nuts, legumes, soy, whole grains, fruits, vegetables), total energy intake; - Other: multivitamin and/or aspirin use; family history of CHD or stroke; intake of coffee; glycemic index; Limitations:; - No preregistered data analysis plan; Funding:; NIH
Ibsen, 2022^55^; PCS, Sweden, Swedish; Mammography Cohort and Cohort of Swedish Men; Analytic N = 76,122; Participant characteristics:; - Age: 59y; 45-83y; - Female: 46%; - Race and/or ethnicity: NR; - SEP: 18% university education; - BMI: 47% with 18.6-24.9 kg/m^2^; - Health Status: 21% HTN, 10% hypercholesterolemia; Excluded those with missing data, cancer, HF, ischemic heart disease; ±3 SD of mean TEI on log scale | Exposure: Red meat (meatballs, pork, veal, kidney and other organ meats) and processed meat (sausage, black pudding, liver paste, ham) combined; Comparator: Continuous (100 g/d substitution); - Whole grains: hard bread such as Wasa/crisp bread, whole meal bread, oatmeal, wheat bran; Assessment methods and timing:; - FFQ at baseline (and some participants at 12y follow-up); Outcome assessment methods and timing:; - Heart failure from Swedish Patient Register validated against medical records; - 22y (median) | [underlined: Heart failure] by 100 g/d substitution, HR (95% CI) Whole grains for red and processed meat: 0.92 (0.88, 0.95) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, nut/legumes, whole grains), total energy intake; - Other: use of corticosteroids, aspirin, and/or dietary supplements; hormone replacement therapy (women); family history of myocardial infarction; history of HTN, hypercholesterolemia, diabetes, and/or atrial fibrillation; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only for unknown proportion of sample; - No preregistered data analysis plan; Funding:; Swedish Research Council; Swedish Research Council for Environment, Agricultural Sciences and Spatial Planning
Wang, 2022^84^; PCS, UK, UK Biobank; Analytic N = 180642; Participant characteristics:; - Age: 55.7 (7.9)y; 40-69y; - Female: 56%; - Race and/or ethnicity: 95% White (all European descent); - SEP: ~1.7 Townsend deprivation index; 55% household income ≥31K£; - BMI: ~27 kg/m^2^; - Health Status: 16% on antihypertensive medication, 13% on cholesterol lowering medication; Excluded those with cancer or CVD, missing dietary data at baseline, <500 or >3500 kcal/d | Exposure: Unprocessed red meat: beef, lamb/mutton, and pork (excluding processed meats); Comparator: Continuous (1 svg/d substitution); - Cereal: details NR, measured in bowls per week; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Mortality (CVD, CHD, and stroke) from death certificate; - 8.6y | [underlined: CVD mortality] by 1 svg/d substitution, HR (95% CI) Cereal for red meat: 0.95 (0.90, 1.00); [underlined: CHD mortality] by 1 svg/d substitution, HR (95% CI) Cereal for red meat: 0.91 (0.84, 0.98); [underlined: Stroke mortality] by 1 svg/d substitution, HR (95% CI) Cereal for red meat: 0.92 (0.82, 1.04) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (household income, deprivation index), physical activity, anthropometry, smoking, alcohol, total energy intake; - Other: UK Biobank assessment center; Limitations:; - Did not account for key confounders: Diet quality; - Only baseline exposure measurements used in primary analysis; - Did not account for loss to follow-up; - No preregistered data analysis plan; Funding:; NHLBI; NIDDK; Fogarty International Center
Wang, 2024^83^; PCS, United States, Million Veteran Program; Analytic N = 148,506; Participant characteristics:; - Age: 61y; - Female: 12%; - Race and/or ethnicity: 81% White; 13% African American; 7% Hispanic; 1% Asian; 1% American Indian; 3% Other; - SEP: 50% college or above; 58% married; 33% family income ≥$60K/y; - BMI: ~28 kg/m^2^; - Health Status: 38% HTN; 35% hypercholesterolemia; Excluded those with missing data, diabetes, cancer, CVD, energy intake <400 or ≥4000 kcal/d (women) or <450 or ≥4500 kcal/d (men) | Exposure: Red meat: unprocessed and processed red meat; Unprocessed red meat: beef, pork, and lamb as a main dish, sandwich, or mixed dish (3oz svg); hamburger patty; Processed red meat: bacon, hot dogs, sausage, salami, bologna, and other processed red meats; Comparator: Continuous (0.5 svg/d substitution); - Whole grains: details NR; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and nonfatal, including myocardial infarction and acute ischemic stroke) from National Death Index and validated high-throughput phenotyping algorithm; - 3.8y | [underlined: Incident CVD] by 0.5 svg/d substitution, RR (95% CI); Whole grains for total red meat: 0.93 (0.89, 0.96); Whole grains for unprocessed red meat: Reduced risk (data NR, figure only), P<0.05; Whole grains for processed red meat: Reduced risk (data NR, figure only), P<0.05 | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education, income, marriage status), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, nuts, yogurt, whole grain, legume, skim milk, eggs, nonskin chicken, fish, SSB), total energy intake; - Other: history of HTN or hypercholesterolemia; Limitations:; - Exposure measured at baseline only; - Inadequate adjustment for missing data; - No preregistered data analysis plan; Funding:; U.S. Department of Veterans Affairs
Zhong, 2021^87^; PCS, United States, Multiple cohorts (ARIC, CARDIA, CHS, FHS, FOS, MESA); Analytic N = 29,682; Participant characteristics:; - Age: 53.7 (15.7)y; - Female: 56%; - Race and/or ethnicity: 69% non-Hispanic White; 24% non-Hispanic Black; 4.5% Hispanic; 2% Chinese; <1% Other; - SEP: 53% some college or more; 47% high school or less; - BMI: NR; - Health Status: Generally healthy; Excluded those with CVD at baseline, missing data, or <500 or >6000 kcal/d | Exposure: Processed meat: 1 svg equivalent to two slices of bacon, two small links of sausage or one hot dog; Unprocessed red meat: details NR; 1 svg equivalent to 85.05 g (i.e., 3 oz); Comparator: Continuous (1 svg/wk substitution); - Whole grains: details NR; 1 svg equivalent to 1 slice of whole grain bread or 1 cup of ready-to-eat whole grain cereal; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and non-fatal CHD, fatal and non-fatal stroke, fatal and non-fatal heart failure, and other CVD deaths) from medical records and/or autopsy data; - 19y | [underlined: Incident CVD] by 1 svg/wk substitution, HR (95% CI); Whole grains for processed meat: 0.96 (0.94, 0.98), P<0.01; Whole grains for unprocessed red meat: 0.99 (0.98, 1.00), P<0.01; Results also provided for 1 svg/d substitution, as well as absolute risk difference. | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, smoking, alcohol, diet quality (AHEI), total energy intake; - Other: cohort; other foods (eggs, processed meat, unprocessed red meat, poultry, fish, nuts, legumes, whole grains); hormone therapy; Limitations:; - Did not account for key confounders: Anthropometry; - Exposure measured at baseline only; - Inadequate information on amount of missingness; - No preregistered data analysis plan; Funding:; AHA Strategically Focused Research Network; NHLBI; Northwestern University Feinberg School of Medicine
Zhu, 2022^88^; PCS, Multiple (Finland, UK, New Zealand, Australia), Secondary analysis of PREVIEW trial; Analytic N = 668; Participant characteristics:; - Age: 57y; 26-70y; - Female: 69%; - Race and/or ethnicity: 86% Caucasian; 3% Black; 3% Asian; 7% Other; 1% Arabic; - SEP: NR; - BMI: 29.5 kg/m^2^; - Health Status: 100% prediabetes; Excluded those <25 or >70y; BMI <25 kg/m^2^; without prediabetes based on ADA 2022 criteria; type 1 or type 2 diabetes; missing dietary data; <600 or >3500 kcal/d for women, or <800 or >4200 kcal/day for men | Exposure: Processed meat: frankfurters, sausage, bacon, corned beef, cured ham and luncheon meat made from beef, pork, poultry; Comparator: Continuous (60-72 kcal/d substitution); - Grains: bread rolls/baps/bagels, breads, cereal bars, cereal products, cereals, crackers/crispbreads, flours, grains, pastas, pastries/buns, rice, pastry, plain cake, biscuits, and starch-based carbohydrate-rich snacks, potatoes, potato products; Assessment methods and timing:; - 4d diet records at 25, 52, 104, and 156wk (cumulative average); Outcome assessment methods and timing:; - TG from fasting blood collection at 8, 26, 52, 104, and 156wk; - 3y | [underlined: TG (mmol/L)] by 60-72 kcal/d substitution, Mean change per year (95% CI); Grains for processed meat: −0.02 (−0.04, 0.01), P=0.272 | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, alcohol, diet quality (intake of animal-based food, grains, legumes, nuts, fruit, vegetables, and sugar), total energy intake; - Other: intervention center, yearly weight change; Limitations:; - Did not account for key confounders: Socioeconomic position, smoking; - No preregistered data analysis plan; Funding:; EU framework programme 7; National Health and Medical Research Council; The Glycemic Index Foundation Australia; The New Zealand Health Research Council; University of Auckland Faculty Research Development Fund; Danish Agriculture & Food Council; Danish Meat and Research Institute; National Institute for Health Research Biomedical Research Centre; Engineering and Physical Sciences Research Council

a Abbreviations: AHEI: Alternative Healthy Eating Index; BMI: body mass index; CABG: coronary artery bypass grafting; CHD: coronary heart disease; CHO: carbohydrate; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DBP: diastolic blood pressure; dL: deciliter(s); DM: diabetes mellitus; eq: equivalent; FFQ: food frequency questionnaire; HDL: high-density lipoprotein cholesterol; HTN: hypertension; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); m: meter(s); L: liter(s); LDL: low-density lipoprotein cholesterol; MI: myocardial infarction; mmHg: millimetre of mercury; mmol: millimole(s); mo: month(s); MUFA: monounsaturated fatty acids; NCC: nested case control; NR: not reported; NS: not significant; OR: odds ratio; oz: ounce(s); P: p-value; PCS: prospective cohort study; PUFA: polyunsaturated fatty acids; RCT: randomized controlled trial; RR: risk ratio; SBP: systolic blood pressure; SD: standard deviation; SEM: standard error of the mean; SFA: saturated fatty acids; SEP: socioeconomic position; SSB: sugar-sweetened beverages; svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; TG: triglycerides; wk: week(s); y: year(s)

Table 57 Risk of bias for observational studies examining red meat compared to whole grains and cereals in adults and older adults and risk of cardiovascular disease^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Al-Shaar, 2020^53^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Ibsen, 2022^55^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Wang, 2022^84^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Wang, 2024^83^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Zhong, 2021^87^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zhu, 2022^88^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 58 Evidence examining the relationship between red meat compared to white meat in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention/Exposure and Comparator | Results | Methodological Considerations
RANDOMIZED CONTROLLED TRIALS
Bergeron, 2019^58^; RCT-crossover, United States, APPROACH (Animal and Plant Protein and Cardiovascular Health); Analytic N = 113; Adequately powered: No; Study aims: To test for differences in lipoprotein effects of diets in which the main source of protein is red meat compared with diets with similar total protein content derived from white meat (poultry) or plant protein sources, and to determine whether these effects were modified by high compared with low SFA intake.; Participant characteristics:; - Age: ~44 (12)y; 21-65y; - Female: 61%; - Race and/or ethnicity: 55% White, 20% Asian, 12% African American, 13% Other; - SEP: NR; - BMI: 26 (3.8) kg/m^2^; 42% with overweight, 16% with obesity; - Health Status: Majority normotensive; Excluded those using tobacco or recreational drugs; lipid-, glucose-, or blood-pressurelowering medications, blood thinners, or hormones; unwillingness to consume all key study foods; weight loss >3% body weight in 3mo preceding study onset; history of coronary artery disease, diabetes, or other chronic disorder; BMI <20 or >35 kg/m^2^; blood pressure ≥150/90; fasting glucose ≥7 mmol/L, total and LDL cholesterol >95^th^% for sex and age; fasting triacylglycerol ≥5.65 mmol/L; unwillingness to refrain from use of vitamin supplements and alcoholic beverages during study | Intervention: Lean red meat: 11% energy from lean cuts of grain-finished beef and 1% energy from lean cuts of pork; Comparator: Lean white meat: 8% energy from chicken and 4% energy from turkey; Other Comparator: Non-meat sources of protein: legumes, nuts, grains, isoflavonefree soy products; 2-3% of energy from SFA was derived from tropical oils and fats with the remainder from high-fat dairy; Fish, seafood, and processed meats were excluded from all diets. For all diets, the remaining protein (~13% energy) was derived from eggs, dairy, and vegetable sources). Differences in SFA content between the high- and low-SFA arms were achieved primarily by using high-fat dairy products and butter, with only 2-3% energy from SFAs derived from lean red or white meat.; Duration: 4wk each (2-7wk washout) Compliance: Yes, using 24h urinary urea nitrogen and creatinine concentrations to monitor protein intake and weekly collection of menu checklists, grocery receipts, and reported deviations from dietary instructions; Outcome assessment methods and timing:; - LDL, HDL, TG, SBP, DBP; - Fasting blood collection and blood pressure at baseline and 4wk postbaseline | [underlined: LDL (mmol/L)], Mean difference (SE) at 4 wk; Red meat−Non-meat: 0.16 (0.03), P<0.0001; White meat−Non-meat: 0.16 (0.03), P<0.0001; [underlined: HDL (mmol/L)], Mean difference (SE) at 4wk; Red meat−Non-meat: 0.03 (0.01), P=0.007; White meat−Non-meat: 0.04 (0.01), P=0.001; [underlined: TG (mmol/L)], Mean difference (SE) at 4wk; Red meat−Non-meat: −0.03 (0.02), P=0.15; White meat−Non-meat: −0.03 (0.02), P=0.17; [underlined: SBP (mmHg)], Mean (SD) at 4 wk; Non-meat vs. white-meat vs. red meat, between groups: P=0.48; [underlined: DBP (mmHg)], Mean (SD) at 4 wk; Non-meat vs. white-meat vs. red meat, between groups: P=0.87 | Limitations:; - Not sufficiently powered; Funding:; NIH
Mateo-Gallego, 2012^68^; RCT-crossover, Spain; Analytic N = 34; Adequately powered: Yes; Study aims: To examine the effects of the incorporation in the usual diet of lean red meat (leg and shoulder of lamb) and lean white meat (chicken) on blood lipids in a group of nuns living in convents.; Participant characteristics:; - Age: 71y; 33-79y; - Female: 100%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 30.1 (5.2) kg/m^2^; - Health Status: 8% with T2D; Excluded those with uncontrolled hypothyroidism and type 2 diabetes (HbA1c >8%), or any other disease that could interfere with the ability to comply with the study protocol. | Intervention: Lamb: 125g, 3 times/week (roasted, grilled, or stewed); Comparator: Chicken: 125g, 3 times/week (roasted, grilled, or stewed); Duration: 5wk each (no washout); Compliance: Yes, FFQ, 3d food record, & convent cook training; Outcome assessment methods and timing:; - LDL, HDL, TG; - Fasting blood collection at baseline and after each 5 wk intervention | [underlined: LDL (mg/L)], Median (SD); Baseline: 1160 (58); Within group: 5wk, change from baseline; Lamb: 1190 (64), P=NS; Chicken: 1190 (54), P=NS; Between group: 5wk; P=0.463; [underlined: HDL (mg/L)], Median (SD); Baseline: 554 (19); Within group: 5wk, change from baseline; Lamb: 526 (17), P<0.016; Chicken: 518 (17), P<0.016; Between group: 5wk; P=0.009; [underlined: TG (mg/L)], Median (IQR); Baseline: 660 (420–900); Within group: 5wk, change from baseline; Lamb: 580 (430- 915), P=NS; Chicken: 630 (495-1030), P=NS; Between group: 5wk; P=0.529 | Limitations:; - No preregistered data analysis plan; Funding:; Ministerio de Ciencia e Innovación, Spain
Mesana Graffe, 2013^69^; RCT-crossover, Spain; Analytic N = 50; Adequately powered: NR; Study aims: To compare the change effect of lamb versus commercial chicken consumption on body composition and cardiovascular risk indicators as part of a usual and balanced diet.; Participant characteristics:; - Age: 19.5 (0.89)y; 16-24y; - Female: 56%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 23.1 (3.55) kg/m^2^; - Health Status: All not taking lipid medications; Excluded those with any chronic, metabolic, endocrine or nutrition related disease, enrolled in a weight loss program, or currently taking any medications known to have a lipid-lowering effect | Intervention: Lamb: 150g, 3 times/week (roasted, grilled, or stewed); Comparator: Chicken: 150g, 3 times/week (roasted, grilled, or stewed); Duration: 8wk each (5wk washout); Compliance: Yes, 100% with “acceptable compliance”, 24h recalls at beginning, middle, and end of each phase; Outcome assessment methods and timing:; - LDL, HDL, TG; - Fasting blood collection at baseline and after each 8 wk intervention | [underlined: LDL (mg/dL)], Mean (SD); Within group: baseline, follow-up; Lamb: 99.2 (27.2), 92.7 (27.2); Chicken: 93.9 (26.0), 96.1 (29.3); Between group: change over 8wk; Lamb: −3.9 (15.4); Chicken: 1.5 (16.9); P=NS; [underlined: HDL (mg/dL)], Mean (SD); Within group: baseline, follow-up; Lamb: 48.4 (13.4), 49.1 (12.6); Chicken: 49.5 (12.8), 49.2 (12.2); Between group: change over 8wk; Lamb: 1.9 (8.3); Chicken: −0.6 (8.9); P=NS; [underlined: TG (mg/dL)], Mean (SD); Within group: baseline, follow-up; Lamb: 77.7 (32.5), 67.5 (32.7); Chicken: 72.3 (36.4), 76.0 (52.8)); Between group: change over 8wk; Lamb: −8.85 (20.4); Chicken: 4.2 (43.2); P<0.05 | Limitations:; - No preregistered data analysis plan; Funding:; INIA (Instituto Nacional de Investigación y Tecnología Agraria y Alimentaria), Fondo Europeo de Desarrollo Regional (FEDER)
O’Connor, 2018^72^; RCT-crossover, United States; Analytic N = 41; Adequately powered: Yes; Study aims: To investigate the effects of consuming different amounts of lean, unprocessed red meat in a Mediterranean Pattern on cardiometabolic disease risk factors; Participant characteristics:; - Age: 46 (2)y; 30-69y; - Female: 68%; - Race and/or ethnicity: 98% White; - SEP: NR; - BMI: 30.5 (0.6) kg/m^2^; - Health Status: All without diabetes; Excluded those already following Mediterranean diet pattern; those with acute illness; smokers; abnormal liver or kidney function; with DM. Included those with overweight or obesity (BMI 25-37); total-C <6.70 mmol/L; LDL <4.10 mmol/L; TG <4.5 mmol/L; fasting glucose <6.1 mmol/L; SBP <160 mmHg; DBP <100 mmHg, body mass <140kg. | Intervention: Med-Red: 476 g/wk of lean, unprocessed red meat (beef or pork tenderloins) and 112 g/wk of lean, unprocessed poultry (chicken or turkey breasts with the skin removed); Comparator: Med-Control: 196 g/wk of lean, unprocessed red meat (beef or pork tenderloins) and 420 g/wk of lean, unprocessed poultry (chicken or turkey breasts with the skin removed) Both diets were adjusted to match energy and macronutrients and prescribed similar daily or weekly servings of other food groups (e.g., fruit, vegetables, whole grains, olive oil); the diets differed predominately in the amounts of red meat and poultry provided.; Duration: 5wk each (≥4wk washout); Compliance: Yes, ≥95% compliance for each diet (dietary intake and compliance measured with menu checklist during last week of intervention); Outcome assessment methods and timing:; - LDL, HDL, TG, SBP, DBP; - Fasting blood collection and BP measurements at baseline and after each 5wk diet period; Results also provided for fasting (N=41), waking (N=40), and sleeping (N=38) SBP and DBP | [underlined: LDL (mmol/L)], Mean (SEM); Within group: baseline, 5wk; Med-Red: 3.1 (0.1), 2.8 (0.1), P<0.05; Met-Control: 3.0 (0.1), 3.0 (0.1), P=NS; Between group: change over 5wk; Med-Red: −0.3 (0.1); Med-Control: −0.1 (0.1); P-interaction=0.038; [underlined: HDL (mmol/L)], Mean (SEM); Within group: baseline, 5wk; Med-Red: 1.2 (0.1), 1.1 (0.0), P=NS; Med-Control: 1.2 (0.1), 1.1 (0.0), P=NS; Between group: change over 5wk; Med-Red: −0.1 (0.0); Med-Control: −0.1 (0.0); P-interaction=0.622; [underlined: TG (mmol/L)], Mean (SEM); Within group: baseline, 5wk; Med-Red: 1.4 (0.1), 1.3 (0.1), P=NS; Med-Control: 1.3 (0.1), 1.2 (0.1), P=NS; Between group: change over 5wk; Med-Red: −0.1 (0.1); Med-Control: −0.1 (0.1); P-interaction=0.579; [underlined: SBP (mmHg)], 24-hr, Mean (SEM); Within group: baseline, 5wk; Med-Red: 130 (2), 126 (2), P=NS; Med-Control: 131 (2), 126 (2), P=NS; Between group: change over 5wk; Med-Red: −5 (2); Med-Control: −5 (2); P-interaction=0.829; [underlined: DBP (mmHg)], 24-hr, Mean (SEM); Within group: baseline, 5wk; Med-Red: 79 (1), 75 (1), P=NS; Med-Control: 78 (1), 75 (1), P=NS; Between group: change over 5wk; Med-Red: −4 (1); Med-Control: −2 (1); P-interaction=0.155 | Limitations:; - Insufficient information on allocation concealment; Funding:; Beef Checkoff; Pork Checkoff; Ingestive Behavior Research Center at Purdue University; Indiana Clinical and Translational Sciences Institute
Santaliestra-Pasías, 2022^78^; RCT-crossover, Spain, DIETAPYR2 study; Analytic N = 47; Adequately powered: NR; Study aims: To evaluate the specific effect of the consumption of the Pirenaica breed in healthy adults on their body composition, cardiovascular risk indicators and fatty acid profiles compared with the consumption of conventional chicken.; Participant characteristics:; - Age: 19.9 (1.8)y; 18-27.5y; - Female: 49%; - Race and/or ethnicity: NR; - SEP: 53% medium maternal education; 44% medium paternal education; - BMI: ~23.3 (3.4) kg/m^2^; - Health Status: Generally healthy; Excluded those younger than 18y or with a chronic, metabolic, endocrine or nutritionrelated disease | Intervention: Beef, lean: 200g (with bones) (from the Pirenaica breed), 3 times/week; loin, silverside, and brisket (grilled, breaded and deep-frieed, or stewed); Comparator: Chicken: 150g (boneless), 3 times/week; thigh, drumstick, and breast (grilled, breaded and deep-fried, or stewed); Duration: 8wk each (5wk washout) Compliance: Yes, 100% with acceptable compliance; Outcome assessment methods and timing:; - LDL, HDL, TG, SBP, DBP; - Fasting blood collection at baseline and after each 8wk intervention | [underlined: LDL (mg/dL)]; Within group: Mean (SD) at baseline, 8wk; Beef: 83.3 (21.3), 80.0 (21.4), P=0.147; Chicken: 77.7 (33.9), 74.5 (31.3), P=0.164; Between group: Mean difference (95% CI) in first 8wk period; 0.159 (−6.15, 6.47), P=0.960; [underlined: HDL (mg/dL)]; Within group: Mean (SD) at baseline, 8wk; Beef: 56.9 (15.2), 57.1 (14.5), P=0.901; Chicken: 56.9 (14.7), 56.5 (13.8), P=0.741; Between group: Mean difference (95% CI) over 8wk; −0.57 (−4.38, 3.24), P=0.765; [underlined: TG (mg/dL)]; Within group: Mean (SD) at baseline, 8wk; Beef: 70.3 (26.3), 81.3 (37.0), P=0.007; Chicken: 75.1 (38.8), 79.7 (32.1), P=0.182; Between group: Mean difference (95% CI) over 8wk; −6.09 (−17.39, 5.22), P=0.284; [underlined: SBP (mmHg)]; Within group: Mean (SD) at baseline, 8wk; Beef: 116 (15.3), 117 (14.0), P=0.402; Chicken: 110 (10.2), 113 (9.8), P=0.023; Between group: Mean difference (95% CI) in first 8wk period; 1.927 (−2.20, 6.05), P=0.352; [underlined: DBP (mmHg)]; Within group: Mean (SD) at baseline, 8wk; Beef: 67.2 (5.3), 68.4 (6.2), P=0.362; Chicken: 66.8 (6.9), 67.0 (6.8), P=0.860; Between group: Mean difference (95% CI) in first 8wk period; −1.019 (−4.66, 2.62), P=0.576 | Limitations:; - Some period or carryover effects identified; Funding:; European Regional Development Fund
Scott, 1994^79^; RCT-parallel, United States; Analytic N = 38; Adequately powered: Yes; Study aims: To assess the effect of beef or chicken on plasma lipid levels in hypercholesterolemic men when consumed as part of a Step I Diet (8-10% of energy intake from saturated fatty acids); Participant characteristics:; - Age: Mean NR; 20-55y; - Female: 0%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: NR; - Health Status: All normotensive; Excluded those who reported use of a lipidlowering drug; tobacco use; regular exercise expending >1000 kcal/wk; alcohol intake >2 drinks per day; heart disease, diabetes, or hypothyroidism; LDL <3.87 mmol/L and fasting TG >3.36 mmol/L; did not have a change in LDL of ≥15% between average values for weeks 0 and 1 and weeks 6 and 7 in the study; BP >140/90; body weight not within 30% of ideal based on 1959 Met Life standards | Intervention: Red meat: 85g of lean cooked beef (choice strip loin steak with 8% fat) per 1000 kcal each day, providing 3.59g SFA per 100g; Comparator: White meat: 85g of cooked chicken breast (with 7% total fat) per 1000 kcal each day, providing 2.22g SFA per 100g; All participants consumed their usual diet for 3wk followed by a 5wk stabilization diet (18% of energy intake from SFA) before randomization into the 5wk intervention diets.; Duration: 5wk; Compliance: Yes, 26% reported no deviation from the test diet, 21% reported one deviation, and 53% reported two to four deviations in the beef group; 32%, 36% and 42% reported those numbers of deviations in the chicken group; Outcome assessment methods and timing:; - LDL, HDL, TG; - Fasting blood collection at baseline (01wk), after stabilization diet (7-8wk), and after intervention diet (12-13wk) | [underlined: LDL (mmol/L)], Mean (SD); Within group: baseline, 7-8wk (poststabilization), 12-13wk (post-intervention); Beef: 4.66 (0.36), 4.93 (0.35), 4.47 (0.42), P<0.0002; Chicken: 4.74 (0.48), 4.93 (0.68), 4.38 (0.63), P<0.0002; Between group: change over 5wk (poststabilization minus post-intervention); Beef: 0.46 (0.43); Chicken: 0.55 (0.35); P=NS; [underlined: HDL (mmol/L)], Mean (SD); Within group: baseline, 7-8wk (poststabilization), 12-13wk (post-intervention); Beef: 1.27 (0.29), 1.25 (0.28), 1.19 (0.27), P<0.02; Chicken: 1.16 (0.21), 1.18 (0.22), 1.06 (0.18), P<0.02; Between group: change over 5wk (poststabilization minus post-intervention); Beef: 0.06 (0.11); Chicken: 0.12 (0.15); P=NS; [underlined: TG (mmol/L)], Mean (SD); Within group: baseline, 7-8wk (poststabilization), 12-13wk (post-intervention); Beef: 1.58 (0.63), 1.74 (0.70), 1.72 (0.63), P=0.87; Chicken: 1.56 (0.56), 1.54 (0.59), 1.46 (0.55), P=0.23; Between group: change over 5wk (poststabilization minus post-intervention); Beef: 0.02 (0.54); Chicken: 0.08 (0.28); P=NS | Limitations:; - Insufficient information on randomization and allocation procedures; - No preregistered data analysis plan; Funding:; National Live Stock and Meat Board
OBSERVATIONAL STUDIES
Al-Shaar, 2020^53^; PCS, United States, HPFS; Analytic N = 43,272; Participant characteristics:; - Age: 53 (9.5)y; 40-75y; - Female: 0%; - Race and/or ethnicity: 95% White; “mostly non-Hispanic”; - SEP: All health professionals; - BMI: 25.5 (3.3) kg/m^2^; - Health Status: 20% history of HTN, 10% high cholesterol; Excluded those with missing data; energy intake <800 or >4200 kcal/d; history of cancer, myocardial infarction, angina, CABG, or stroke | Exposure: Total red meat: processed and unprocessed red meat; Unprocessed red meat: hamburger (lean or extra lean), regular hamburgers, beef, pork, or lamb as a sandwich or main or mixed dish (e.g., stew, casserole, lasagna, frozen dinners, etc).; Processed red meat: beef or pork hotdogs, bacon, salami, bologna, other processed meat sandwiches, other processed meats (e.g., sausages, kielbasa, etc); Comparator: Continuous (1 svg/d substitution); - Poultry: unprocessed; chicken/turkey sandwich or frozen dinner; other chicken or turkey, with skin -including ground; other chicken or turkey, without skin; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - CHD (acute non-fatal MI or fatal CHD) from physician review of medical records, telephone interview of supplemental information, death certificate; - 30y | [underlined: CHD] by 1 svg/d substitution, HR (95% CI); Poultry for total red meat: 0.92 (0.81, 1.05), P=0.24; Poultry for unprocessed red meat: 0.92 (0.79, 1.06), P=0.24; Poultry for processed red meat: 0.89 (0.77, 1.02), P=0.10 | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (marital status, living arrangement, profession, work status), physical activity, anthropometry, smoking, alcohol, diet quality (intakes of poultry, fish, egg, high fat dairy, low fat dairy, nuts, legumes, soy, whole grains, fruits, vegetables), total energy intake; - Other: multivitamin and/or aspirin use; family history of CHD or stroke; intake of coffee; glycemic index; Limitations:; - No preregistered data analysis plan; Funding:; NIH
Bernstein, 2010^34^; PCS, United States, NHS; Analytic N = 84,136; Participant characteristics:; - Age: ~58y; 30-55y; - Female: 100%; - Race and/or ethnicity: Mostly White; - SEP: All nurses/health professionals; - BMI: ~26 kg/m^2^; - Health Status: 34% history of high BP; 36%history of high cholesterol; Excluded participants with incomplete FFQ; implausible TEI; previously diagnosed cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of coronary artery bypass grafting) | Exposure: Red meat: hamburger, beef hot dog, processed meat, and processed meat sandwich, bacon, beef/pork/lamb as a mixed and main dish; Comparator: Continuous (1 svg/d substitution); - Poultry: chicken with and without skin, chicken sandwich, and chicken/turkey hot dog; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - CHD (nonfatal MI and fatal CHD) from medical records, state vital records, National Death Index, postal system or report by kin; - 26y | [underlined: CHD] by 1 svg/d substitution, RR (95% CI) Poultry for red meat: 0.81 (0.67, 0.97) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, trans fat), total energy intake; - Other: time period, menopausal status, parental history of early myocardial infarction, years of multivitamin use, vitamin E supplement use, aspirin use; Limitations:; - Did not account for key confounders: Socioeconomic position; - No preregistered data analysis plan; Funding:; NIH; Unilever
Bernstein, 2012^54^; PCS, United States, NHS, HPFS; Analytic N = 127,160; Participant characteristics:; - Age: NHS ~57y, 30-55y; HPFS ~62y, 4075y; - Female: 66%; - Race and/or ethnicity: Mostly White; - SEP: All nurses/health professionals; - BMI: ~26 kg/m^2^; - Health Status: ~33% high BP (HPFS & NHS); ~38% high cholesterol (HPFS), 35% high cholesterol (NHS); Excluded participants diagnosed with cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of percutaneous coronary intervention or coronary artery bypass grafting) at baseline; excessive missing data on FFQ; implausible energy intake | Exposure: Red meat: unprocessed red meat (hamburger, beef, pork, and lamb), processed red meat (beef hot dog, processed meats such as bologna and salami, and bacon); Comparator: Continuous (1 svg/d substitution); - Poultry: chicken with and without skin, chicken sandwich, and chicken/turkey hot dog; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - Stroke [ischemic (thrombotic, embolic, or unspecified non-hemorrhagic), hemorrhagic, or of unknown type] from medical records, autopsy report, death certificate, or report by next-of-kin; - 22-26 y | [underlined: Stroke] by 1 svg/d substitution, HR (95% CI) Poultry for red meat: 0.73 (0.61, 0.88) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, fruit and vegetables, trans fat, other protein sources), total energy intake; - Other: time period, parental history of MI (<60y), menopausal status (women), multivitamin use, vitamin E supplement use, aspirin use; Limitations:; - Did not account for key confounders: Socioeconomic position; - Unclear how many participants were excluded for exposure missingness vs. previous diagnosis of a condition; - No preregistered data analysis plan; Funding:; NIH; Harvard Human Nutrition Program
Borgi, 2015^59^; PCS, United States, NHS, NHS II, HPFS; Analytic N = 188,518 (62,273 from NHS I; 88,831 from NHS II; 37,414 from HPFS); Participant characteristics:; - Age: ~36-55y (mean across cohorts and meat, poultry, seafood intake); 25-75y at enrollment; - Female: 80%; - Race and/or ethnicity: ~94% White; mostly non-Hispanic; - SEP: All nurses/health professionals; - BMI: ~23-25 kg/m^2^; - Health Status: All without HTN at baseline; Excluded those with diagnosis of hypertension at baseline; those who did not provide dietary information | Exposure: Total red meat (unprocessed and processed meats, including bacon, hot dogs, hamburgers, beef, pork, lamb); 1 serving (amount NR); Comparator: Continuous (1 svg/d substitution); - Poultry (chicken and turkey, with or without skin); Assessment methods and timing:; - FFQ at baseline and every 4y; Outcome assessment methods and timing:; - HTN self-reported on annual questionnaires; - 20-26y | [underlined: Incident HTN] by 1 svg substitution, HR (95% CI); Poultry for meat; NHS: Data NR (figure only), P=NS; NHS II: Data NR (figure only), P=NS; HPFS: Data NR (figure only), P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (fruits and vegetables, whole grains, SSB, artificially sweetened beverages), total energy intake; - Other: family history of HTN; post-menopausal status; oral contraceptive use (in NHS II); use of non-narcotic analgesic use; change in weight; Limitations:; - Did not account for key confounders: Socioeconomic position; - Outcome was self-reported; - No preregistered data analysis plan; Funding:; AHA
Bouillon, 2011^60^; PCS, UK, Whitehall II; Analytic N = 4469; Participant characteristics:; - Age: 49.3y; 39-62y; - Female: 38%; - Race and/or ethnicity: 94% White; 6% nonWhite; - SEP: 44% no or lower secondary education, 26% A-levels, 30% university or higher; - BMI: 25.0 (3.5) kg/m^2^ (45% with overweight or obesity); - Health Status: 33% with long-standing illness; Excluded those with missing data | Exposure: Ratio of white to red meat (as one of the 9 components of AHEI); Comparator: Categorical (standardised to a z-score and categorized as ‘increase’ (zscore ≥1), ‘stable’ (−1≤ z-score <1) and ‘decrease’ (z-score ≤-1)); Assessment methods and timing:; - FFQ at baseline and 11y follow-up; Outcome assessment methods and timing:; - LDL from fasting blood collection at baseline and 11y follow-up; - 11.3y | [underlined: LDL (mmol/L)] by ratio of white to red meat, Mean absolute change (95% CI); Increase (≥1 SD): −1.67 (−1.79, −1.56), P<0.001; Stable (−1≤SD<1): −1.55 (−1.65, −1.45), REF; Decrease (<-1 SD): −1.51 (−1.62, −1.39), P=0.17 | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry; - Other: duration of followup, longstanding illness at baseline; lipid lowering drug use; Limitations:; - Did not account for key confounders: Smoking, alcohol, diet quality, total energy intake; - Exposure not well-defined; - No preregistered data analysis plan; Funding:; Medical Research Council (UK); Economic and Social Research Council (UK); British Heart Foundation; Health and Safety Executive (UK); Department of Health (UK); BUPA Foundation, UK; NHLBI; NIA
Haring, 2014^38^; PCS, United States, ARIC; Analytic N = 12,066; Participant characteristics:; - Age: ~53.8 (5.7)y; 45-64y; - Female: 56%; - Race and/or ethnicity: 77% White; 23% Black; - SEP: 79% high school graduates; - BMI: 27.1 kg/m^2^; - Health Status: 29% HTN; ~26% current smoker; Excluded participants with self-reported diabetes, fasting blood glucose ≥126 mg/dL, non-fasting blood glucose ≥200 mg/dL or use of diabetes medication, a history of myocardial infarction, stroke, heart failure, coronary bypass surgery, angioplasty or with missing data on covariates of interest, implausible energy intake or incomplete dietary information | Exposure: Processed red meat: details NR Red meat: unprocessed, details NR; Comparator: Continuous (1 svg/d substitution); - Poultry: details NR but presumably unprocessed; Assessment methods and timing:; - FFQ at baseline and ~6y follow-up (cumulative average); Outcome assessment methods and timing:; - CHD (definite or probable MI, or CHD death) adjudicated using information from study visits, yearly telephone follow-up calls, review of hospital discharge lists and medical charts, death certificates, next-of-kin interviews, and physician-completed questionnaires; - 22y | [underlined: CHD] by 1 svg/d substitution, HR (95% CI) Poultry for processed meat: 0.93 (0.73, 1.18) Poultry for red meat: 0.81 (0.62, 1.07) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (all the food items in the table, fiber intake), total energy intake; - Other: study center, systolic blood pressure, use of antihypertensive and/or lipid lowering medication, HDL, total cholesterol, carbohydrate intake, magnesium intake; Limitations:; - No preregistered data analysis plan; Funding:; NHLBI/NIH; German Research Foundation; University of Wurzburg
Key, 2019^56^; PCS, Multiple (9 European countries), EPIC; Analytic N = 409,885; Participant characteristics:; - Age: 52.7 (10.3)y in men, 51.3 (9.8)y in women; - Female: 74%; - Race and/or ethnicity: NR; - SEP: 46% vocational or university education; - BMI: 26.6 (3.7) kg/m^2^ in men, 25.0 (4.4) kg/m^2^ in women; - Health Status: 17% HTN, 14% hyperlipidemia; Excluded those with missing data, top or bottom 1% of ratio of energy intake to energy requirement, MI or stroke | Exposure: Red meat: unprocessed (including beef, veal, pork, lamb, mutton, goat, horse, hamburger, meatballs, minced meat) and processed meat (meat products, including poultry, preserved by methods other than freezing, such as salting with or without nitrites, smoking, marinating, air drying, or heating, and including ham, bacon, sausages, blood sausages, chicken sausage, meat cuts, liver paté, salami, bologna, tinned meat, luncheon meat, corned beef and black pudding); Comparator: Continuous (100 kcal/d substitution); - Poultry: white meat, excluding processed poultry; Assessment methods and timing:; - FFQ at baseline (country-specific); Outcome assessment methods and timing:; - Ischemic heart disease (IHD): composite of first non-fatal MI or death from IHD from hospital registries and self-reports confirmed with medical records; mortality registries or follow-up with next of kin; - 12.6y | [underlined: IHD] by 100 kcal/d substitution, HR (95% CI) Poultry meat for red and processed meat: 0.89 (0.76, 1.04) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (employment status, education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit and vegetable intake, sugar, fiber), total energy intake; - Other: history of DM, hypertension, hyperlipidemia, EPIC center, other foods as appropriate (poultry meat, white fish, fatty fish, milk, yogurt, cheese, and eggs); Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only; - Some variations in the ascertainment and validation of the endpoint; - No preregistered data analysis plan; Funding:; UK Medical Research Council; Cancer Research UK; Wellcome Trust; European Union Framework 7; European Research Council; British Heart Foundation; UK National Institute of Health Research; European Commission; International Agency for Research on Cancer
Nielsen, 2021^71^; PCS, Denmark, Danish Diet, Cancer and Health; Analytic N = 54,229; Participant characteristics:; - Age: 56 (4)y; 50-64y; - Female: 53%; - Race and/or ethnicity: NR; - SEP: 62% with medium or long tertiary education; - BMI: 43% with 18.5-25 kg/m^2^; 56% >25 kg/m^2^; - Health Status: 2% T2D; 16% HTN; 7% hypercholesterolemia; Excluded those with previous diagnoses of cancer or CVD (myocardial infarction or stroke) and missing information on covariates | Exposure: Total red meat: unprocessed and processed red meat; Unprocessed red meat: cooked and uncooked red meat, including beef, veal, pork, lamb and offal; Processed red meat: all red meat that had undergone processing such as smoking, salting or curing, including sausages, salami, smoked or cooked ham, bacon and liver pate; Comparator: Continuous (150 g/wk substitution); - Poultry: chicken (meat and skin) and turkey; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD mortality from record linkage to the Danish National Patient Register and the Cause of Death Register; - 16.1y | [underlined: CVD mortality] by 150 g/wk substitution, HR (95% CI); Poultry for total red meat: 1.04 (0.99, 1.10); Poultry for unprocessed red meat: 1.06 (1.01, 1.13); Poultry for processed red meat: 1.00 (0.94, 1.06) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit and vegetable consumption), total energy intake; - Other: hypercholesteraemia, diabetes, HTN; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Diet measured at baseline only; - No preregistered data analysis plan; Funding:; Danish Cancer Society
Sun, 2021^80^; PCS, United States, Women’s Health Initiative; Analytic N = 102,521; Participant characteristics:; - Age: 62 (7)y; 50-79y; - Female: 100%; - Race and/or ethnicity: 82% White; 9% Black; ~4% Hispanic; ~5% Other/Missing; - SEP: 32% high school or less, 27% some college, 40% college or higher; 37% annual income >$50K; - BMI: ~27 (5) kg/m^2^; - Health Status: 48% family history of heart attack; 36% family history of stroke; Excluded those with missing data, energy intake <600 or >5000 kcal/d, CVD or cancer at baseline | Exposure: Total red meat: unprocessed (beef, pork, veal, lamb, and game) and processed (franks, sausages, luncheon meats); computed into ounce equivalent according to protein content (1 oz meat = 1 oz equivalent of protein food); Comparator: Continuous (2 oz-eq/d substitution); - Poultry: chicken, turkey, and other poultry; computed into ounce equivalent according to protein content (1 oz meat = 1 oz equivalent of protein food); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD mortality (included deaths from atherosclerotic cardiac, definite coronary heart disease, possible coronary heart disease, cerebrovascular disease, pulmonary embolism, and other or unknown cardiovascular disease) from death certificates, medical records, autopsy reports, or linkage to National Death Index; - 18.1y | [underlined: CVD mortality] by 2 oz-eq/d substitution, HR (95% CI); Poultry for total red meat: data NR (figure only), P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education, income), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, whole grains, SSB, and other protein sources), total energy intake; - Other: hormone use; family history of heart attack/stroke; Limitations:; - Exposure measured at baseline only; - Data not provided beyond figure; - No preregistered data analysis plan; Funding:; NHLBI
Thao, 2023^81^; PCS, France, E3N; Analytic N = 45,771; Participant characteristics:; - Age: 51.8 (6.3)y; 40-65y; - Female: 100%; - Race and/or ethnicity: NR; - SEP: 36% university education; - BMI: 22.9 (3.2) kg/m^2^; - Health Status: 6% history of CVD; Excluded those with HTN, CVD, stroke, or myocardial infarction; missing dietary data or reporting no meat/fish intake; <1000 or >4000 kcal/d | Exposure: Processed red meat: sausage, ham, charcuterie, and pâté; Comparator: Continuous (150 g/wk substitution); - Poultry: details NR; Assessment methods and timing:; - FFQ at baseline and 12y follow-up (only baseline used in main analysis; followup used in sensitivity analyses); Outcome assessment methods and timing:; - HTN from self-report of date of diagnosis and use of antihypertensive treatments; validated with medication reimbursement; - 18.3y | [underlined: Incident HTN] by 150 g/wk substitution, HR (95% CI); Poultry for processed red meat: 0.99 (0.94, 1.03); Data also provided stratified by BMI, smoking status, and history of diabetes; Secondary analysis also conducted using second FFQ | Model adjustments:; - Key confounders: Sex, age (at menopause), socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (SSB intake), total energy intake; - Other: family history of CVD and prevalent diabetes; use of menopausal hormone therapy; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - No preregistered data analysis plan; Funding:; Mutuelle Générale de l’Education Nationale; European Community; French League against Cancer; Gustave Roussy Institute; French Institute of Health and Medical Research; French Research Agency
van den Brandt, 2019^57^; NCC, The Netherlands, The Netherlands Cohort Study; Analytic N = 8823 deaths and 3202 subcohort members; Participant characteristics:; - Age: 61y; 55-69y; - Female: 60%; - Race and/or ethnicity: NR; - SEP: 16% university or higher vocational education; - BMI: ~25 kg/m^2^; - Health Status: ~25% HTN; ~3% T2D; Excluded those with a history of cancer (excluding skin cancer) or CVD (myocardial infarction, angina pectoris, stroke) at baseline, incomplete or inconsistent dietary data, or missing on confounders | Exposure: Processed meat: meat items that have undergone some form of preservation (mostly treatment with nitrite salt, sometimes smoked or fermented); included ham, bacon, smoked beef or pork loin roll, and other sliced cold meats (e.g., sausages); mainly referred to processed red meat, may contain small amounts of processed white meat (poultry) as in sausages; Comparator: Continuous (50 g/d substitution); - Poultry: unprocessed chicken and turkey; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD mortality determined from linkage with the Dutch Central Bureau of Genealogy and Statistics Netherlands; - 10y | [underlined: CVD mortality] by 50 g/d substitution, HR (95% CI); Poultry for processed meat: 0.76 (0.56, 1.05) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit and vegetable intake), total energy intake; - Other: diabetes, HTN, use of nutritional supplements; postmenopausal HRT in women; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only; - No preregistered data analysis plan; Funding:; NR
Wang, 2022^84^; PCS, UK, UK Biobank; Analytic N = 180642; Participant characteristics:; - Age: 55.7 (7.9)y; 40-69y; - Female: 56%; - Race and/or ethnicity: 95% White (all European descent); - SEP: ~1.7 Townsend deprivation index; 55% household income ≥31K£; - BMI: ~27 kg/m^2^; - Health Status: 16% on anti-hypertensive medication, 13% on cholesterol lowering medication; Excluded those with cancer or CVD, missing dietary data at baseline, <500 or >3500 kcal/d | Exposure: Unprocessed red meat: beef, lamb/mutton, and pork (excluding processed meats); Comparator: Continuous (1 svg/d substitution); - Poultry: details NR, but likely; - unprocessed since processed meat was measured separately; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Mortality (CVD, CHD, and stroke) from death certificate; - 8.6y | [underlined: CVD mortality] by 1 svg/d substitution, HR (95% CI); Poultry for red meat: 0.88 (0.80, 0.96); [underlined: CHD mortality] by 1 svg/d substitution, HR (95% CI); Poultry for red meat: 0.84 (0.74, 0.96); [underlined: Stroke mortality] by 1 svg/d substitution, HR (95% CI); Poultry for red meat: 0.82 (0.68, 1.00) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (household income, deprivation index), physical activity, anthropometry, smoking, alcohol, total energy intake; - Other: UK Biobank assessment center; Limitations:; - Did not account for key confounders: Diet quality; - Only baseline exposure measurements used in primary analysis; - Did not account for loss to follow-up; - No preregistered data analysis plan; Funding:; NHLBI; NIDDK; Fogarty International Center
Wang, 2024^83^; PCS, United States, Million Veteran Program; Analytic N = 148,506; Participant characteristics:; - Age: 61y; - Female: 12%; - Race and/or ethnicity: 81% White; 13% African American; 7% Hispanic; 1% Asian; 1% American Indian; 3% Other; - SEP: 50% college or above; 58% married; 33% family income ≥$60K/y; - BMI: ~28 kg/m^2^; - Health Status: 38% HTN; 35% hypercholesterolemia; Excluded those with missing data, diabetes, cancer, CVD, energy intake <400 or ≥4000 kcal/d (women) or <450 or ≥4500 kcal/d (men) | Exposure: Red meat: unprocessed and processed red meat; Unprocessed red meat: beef, pork, and lamb as a main dish, sandwich, or mixed dish (3oz svg); hamburger patty; Processed red meat: bacon, hot dogs, sausage, salami, bologna, and other processed red meats; Comparator: Continuous (0.5 svg/d substitution); - White meat/poultry: chicken or turkey without skin; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and nonfatal, including myocardial infarction and acute ischemic stroke) from National Death Index and validated high-throughput phenotyping algorithm; - 3.8y | [underlined: Incident CVD] by 0.5 svg/d substitution, RR (95% CI); White meat for red meat: data NR (figure only), P=NS; Results also provided for replacing unprocessed red meat or processed red meat with white meat (data NR, figure only), both P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education, income, marriage status), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, nuts, yogurt, whole grain, legume, skim milk, eggs, nonskin chicken, fish, SSB), total energy intake; - Other: history of HTN or hypercholesterolemia; Limitations:; - Exposure measured at baseline only; - Inadequate adjustment for missing data; - No preregistered data analysis plan; Funding:; U.S. Department of Veterans Affairs
Würtz, 2016b^86^; PCS, Denmark, Danish Diet, Cancer and Health; Analytic N = 55,171 (29,142 women; 26,029 men); Participant characteristics:; - Age: ~56y; 50-64y; - Female: 53%; - Race and/or ethnicity: NR, 100% born in Denmark; - SEP: 32% <8y education; - BMI: ~26 (21-33) kg/m^2^; - Health Status: 2% T2D; 16% HTN; 7% hypercholesterolemia; Excluded those with cancer or MI at baseline, missing baseline data | Exposure: Red meat: unprocessed and processed red meat; Unprocessed red meat: fresh and minced beef, veal, pork, and lamb; Fatty unprocessed red meat: >10g fat per 100g; Processed red meat: red meat items; processed via smoking, salting or curing (sausages, salami, smoked or cooked ham, cold cuts, bacon, liver pate) Poultry: chicken and turkey; Comparator: Continuous (150 g/wk substitution); - Poultry: chicken and turkey; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Myocardial infarction (fatal and nonfatal) from Danish National Patient Register and in the Danish Cause of Death Register; - 13.5y | [underlined: MI] per 150 g/wk substitution, HR (95% CI); Poultry for red meat; All: 1.00 (0.95, 1.05); Women: 0.95 (0.85, 1.06); Men: 1.01 (0.96, 1.07); Poultry for unprocessed red meat; All: 1.01 (0.96, 1.07); Women: 0.93 (0.82, 1.04); Men: 1.03 (0.97, 1.09); Poultry for processed red meat; All: 0.99 (0.93, 1.04); Women: 0.99 (0.86, 1.14); Men: 0.99 (0.92, 1.05) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit, vegetables, sweets, soft drinks, lean and fatty dairy products, fatty potatoes, refined and whole grain cereals, nuts), total energy intake; - Other: menopausal status; HRT use; HTN; Hypercholesterolemia; T2D; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Diet measured at baseline only; - No preregistered data analysis plan; Funding:; Danish Council for Strategic Research; Aarhus University; Danish Cancer Society
Zhong, 2021^87^; PCS, United States, Multiple cohorts (ARIC, CARDIA, CHS, FHS, FOS, MESA); Analytic N = 29,682; Participant characteristics:; - Age: 53.7 (15.7)y; - Female: 56%; - Race and/or ethnicity: 69% non-Hispanic White; 24% non-Hispanic Black; 4.5% Hispanic; 2% Chinese; <1% Other; - SEP: 53% some college or more; 47% high school or less; - BMI: NR; - Health Status: Generally healthy; Excluded those with CVD at baseline, missing data, or <500 or >6000 kcal/d | Exposure: Processed meat: 1 svg equivalent to two slices of bacon, two small links of sausage or one hot dog Unprocessed red meat: details NR; 1 svg equivalent to 85.05 g (i.e., 3 oz); Comparator: Continuous (1 svg/wk substitution); - Poultry: details NR; 1 svg equivalent to 85.05 g (i.e., 3 oz); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and non-fatal CHD, fatal and non-fatal stroke, fatal and non-fatal heart failure, and other CVD deaths) from medical records and/or autopsy data; - 19y | [underlined: Incident CVD] by 1 svg/wk substitution, HR (95% CI); Unprocessed red meat for processed meat: 0.97 (0.95, 1.00), P<0.05; Poultry for processed meat: 0.97 (0.95, 1.00), P<0.05; Poultry for unprocessed red meat: 1.00 (0.99, 1.01); Results also provided for 1 svg/d substitution, as well as absolute risk difference. | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, smoking, alcohol, diet quality (AHEI), total energy intake; - Other: cohort; other foods (eggs, processed meat, unprocessed red meat, poultry, fish, nuts, legumes, whole grains); hormone therapy; Limitations:; - Did not account for key confounders: Anthropometry; - Exposure measured at baseline only; - Inadequate information on amount of missingness; - No preregistered data analysis plan; Funding:; AHA Strategically Focused Research Network; NHLBI; Northwestern University Feinberg School of Medicine
Zhu, 2022^88^; PCS, Multiple (Finland, UK, New Zealand, Australia), Secondary analysis of PREVIEW trial; Analytic N = 668; Participant characteristics:; - Age: 57y; 26-70y; - Female: 69%; - Race and/or ethnicity: 86% Caucasian; 3% Black; 3% Asian; 7% Other; 1% Arabic; - SEP: NR; - BMI: 29.5 kg/m^2^; - Health Status: 100% prediabetes; Excluded those <25 or >70y; BMI <25 kg/m^2^; without prediabetes based on ADA 2022 criteria; type 1 or type 2 diabetes; missing dietary data; <600 or >3500 kcal/d for women, or <800 or >4200 kcal/day for men | Exposure: Processed meat: frankfurters, sausage, bacon, corned beef, cured ham and luncheon meat made from beef, pork, poultry; Comparator: Continuous (60-72 kcal/d substitution); - Poultry: poultry and poultry products, chicken, turkey; Assessment methods and timing:; - 4d diet records at 25, 52, 104, and 156wk (cumulative average); Outcome assessment methods and timing:; - TG from fasting blood collection at 8, 26, 52, 104, and 156wk; - 3y | [underlined: TG (mmol/L)] by 60-72 kcal/d substitution, Mean change per year (95% CI); Poultry for processed meat: −0.03 (−0.06, 0.001), P=0.058 | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, alcohol, diet quality (intake of animal-based food, grains, legumes, nuts, fruit, vegetables, and sugar), total energy intake; - Other: intervention center, yearly weight change; Limitations:; - Did not account for key confounders: Socioeconomic position, smoking; - No preregistered data analysis plan; Funding:; EU framework programme 7; National Health and Medical Research Council; The Glycemic Index Foundation Australia; The New Zealand Health Research Council; University of Auckland Faculty Research Development Fund; Danish Agriculture & Food Council; Danish Meat and Research Institute; National Institute for Health Research Biomedical Research Centre; Engineering and Physical Sciences Research Council

a Abbreviations: AHEI: Alternative Healthy Eating Index; BMI: body mass index; CABG: coronary artery bypass grafting; CHD: coronary heart disease; CHO: carbohydrate; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DBP: diastolic blood pressure; dL: deciliter(s); DM: diabetes mellitus; eq: equivalent; FFQ: food frequency questionnaire; HDL: high-density lipoprotein cholesterol; HTN: hypertension; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); m: meter(s); L: liter(s); LDL: low-density lipoprotein cholesterol; MI: myocardial infarction; mmHg: millimetre of mercury; mmol: millimole(s); mo: month(s); MUFA: monounsaturated fatty acids; NCC: nested case control; NR: not reported; NS: not significant; OR: odds ratio; oz: ounce(s); P: p-value; PCS: prospective cohort study; PUFA: polyunsaturated fatty acids; RCT: randomized controlled trial; RR: risk ratio; SBP: systolic blood pressure; SD: standard deviation; SEM: standard error of the mean; SFA: saturated fatty acids; SEP: socioeconomic position; SSB: sugar-sweetened beverages; svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; TG: triglycerides; wk: week(s); y: year(s)

Table 59 Risk of bias for randomized controlled trial examining red meat compared to white meat in adults and older adults and risk of cardiovascular disease^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (per-protocol)* | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bergeron, 2019^58^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Mateo-Gallego, 2012^68^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Mesana Graffe, 2013^69^ | LOW | LOW | LOW* | LOW | LOW | SOME CONCERNS | SOME CONCERNS
O’Connor, 2018^72^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Santaliestra-Pasías, 2022^78^ | LOW | LOW | LOW | LOW | LOW | HIGH | HIGH
Scott, 1994^79^ | SOME CONCERNS | NOT APPLICABLE | LOW* | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 ) *Deviations from intended interventions (effect of assignment)

Table 60 Risk of bias for observational studies examining red meat compared to white meat in adults and older adults and risk of cardiovascular disease^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Al-Shaar, 2020^53^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bernstein, 2010^34^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bernstein, 2012^54^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Borgi, 2015^59^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Bouillon, 2011^60^ | HIGH | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Haring, 2014^38^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Key, 2019^56^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Nielsen, 2021^71^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Sun, 2021^80^ | LOW* | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Thao, 2023^81^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
van den Brandt, 2019^57^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Wang, 2022^84^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Wang, 2024^83^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Würtz, 2016b^86^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Zhong, 2021^87^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zhu, 2022^88^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 61 Evidence examining the relationship between red meat compared to fish and seafood in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention/Exposure and Comparator | Results | Methodological Considerations
Al-Shaar, 2020^53^; PCS, United States, HPFS; Analytic N = 43,272; Participant characteristics:; - Age: 53 (9.5)y; 40-75y; - Female: 0%; - Race and/or ethnicity: 95% White; “mostly non-Hispanic”; - SEP: All health professionals; - BMI: 25.5 (3.3) kg/m^2^; - Health Status: 20% history of HTN, 10% high cholesterol; Excluded those with missing data; energy intake <800 or >4200 kcal/d; history of cancer, myocardial infarction, angina, CABG, or stroke | Exposure: Total red meat: processed and unprocessed red meat; Unprocessed red meat: hamburger (lean or extra lean), regular hamburgers, beef, pork, or lamb as a sandwich or main or mixed dish (e.g., stew, casserole, lasagna, frozen dinners, etc).; Processed red meat: beef or pork hotdogs, bacon, salami, bologna, other processed meat sandwiches, other processed meats (e.g., sausages, kielbasa, etc); Comparator: Continuous (1 svg/d substitution); - Fish: canned tuna fish; breaded fish cakes, pieces, or fish sticks; other fish (e.g., cod, haddock, halibut); dark meat fish (e.g. mackerel, salmon, sardines, bluefish, swordfish); Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - CHD (acute non-fatal MI or fatal CHD) from physician review of medical records, telephone interview of supplemental information, death certificate; - 30y | [underlined: CHD] by 1 svg/d substitution, HR (95% CI) Fish for total red meat: 1.06 (0.95, 1.19), P=0.31; Fish for unprocessed red meat: 1.05 (0.93, 1.20), P=0.43; Fish for processed red meat: 1.01 (0.88, 1.15), P=0.91; (when stratified by fish type (dark meat, canned tuna, other fish) and follow-up period (<2000 or ≥2000), dark meat fish was associated with lower CHD risk while other fish was associated with higher risk when replacing total red meat, unprocessed, and processed; tuna and <2000 were NS (Table 4 in paper) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (marital status, living arrangement, profession, work status), physical activity, anthropometry, smoking, alcohol, diet quality (intakes of poultry, fish, egg, high fat dairy, low fat dairy, nuts, legumes, soy, whole grains, fruits, vegetables), total energy intake; - Other: multivitamin and/or aspirin use; family history of CHD or stroke; intake of coffee; glycemic index; Limitations:; - No preregistered data analysis plan; Funding:; NIH
Bernstein, 2010^34^; PCS, United States, NHS; Analytic N = 84,136; Participant characteristics:; - Age: ~58y; 30-55y; - Female: 100%; - Race and/or ethnicity: Mostly White; - SEP: All nurses/health professionals; - BMI: ~26 kg/m^2^; - Health Status: 34% history of high BP; 36%history of high cholesterol; Excluded participants with incomplete FFQ; implausible TEI; previously diagnosed cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of coronary artery bypass grafting) | Exposure: Red meat: hamburger, beef hot dog, processed meat, and processed meat sandwich, bacon, beef/pork/lamb as a mixed and main dish; Comparator: Continuous (1 svg/d substitution); - Fish: canned tuna, dark- and light-fleshed fish, and breaded fish; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - CHD (nonfatal MI and fatal CHD) from medical records, state vital records, National Death Index, postal system or report by kin; - 26y | [underlined: CHD] by 1 svg/d substitution, RR (95% CI); Fish for red meat: 0.76 (0.61, 0.94) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, trans fat), total energy intake; - Other: time period, menopausal status, parental history of early myocardial infarction, years of multivitamin use, vitamin E supplement use, aspirin use; Limitations:; - Did not account for key confounders: Socioeconomic position; - No preregistered data analysis plan; Funding:; NIH; Unilever
Bernstein, 2012^54^; PCS, United States, NHS, HPFS; Analytic N = 127,160; Participant characteristics:; - Age: NHS ~57y, 30-55y; HPFS ~62y, 40-75y; - Female: 66%; - Race and/or ethnicity: Mostly White; - SEP: All nurses/health professionals; - BMI: ~26 kg/m^2^; - Health Status: ~33% high BP (HPFS & NHS); ~38% high cholesterol (HPFS), 35% high cholesterol (NHS); Excluded participants diagnosed with cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of percutaneous coronary intervention or coronary artery bypass grafting) at baseline; excessive missing data on FFQ; implausible energy intake | Exposure: Red meat: unprocessed red meat (hamburger, beef, pork, and lamb), processed red meat (beef hot dog, processed meats such as bologna and salami, and bacon); Comparator: Continuous (1 svg/d substitution) Fish: canned tuna, dark and light fleshed fish, and breaded fish; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - Stroke [ischemic (thrombotic, embolic, or unspecified non-hemorrhagic), hemorrhagic, or of unknown type] from medical records, autopsy report, death certificate, or report by next-of-kin; - 22-26 y | [underlined: Stroke] by 1 svg/d substitution, HR (95% CI) Fish for red meat: 0.83 (0.70, 1.00) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, fruit and vegetables, trans fat, other protein sources), total energy intake; - Other: time period, parental history of MI (<60y), menopausal status (women), multivitamin use, vitamin E supplement use, aspirin use; Limitations:; - Did not account for key confounders: Socioeconomic position; - Unclear how many participants were excluded for exposure missingness vs. previous diagnosis of a condition; - No preregistered data analysis plan; Funding:; NIH; Harvard Human Nutrition Program
Borgi, 2015^59^; PCS, United States, NHS, NHS II, HPFS; Analytic N = 188,518; (62,273 from NHS I; 88,831 from NHS II; 37,414 from HPFS); Participant characteristics:; - Age: ~36-55y (mean across cohorts and meat, poultry, seafood intake); 25-75y at enrollment; - Female: 80%; - Race and/or ethnicity: ~94% White; mostly non-Hispanic; - SEP: All nurses/health professionals; - BMI: ~23-25 kg/m^2^; - Health Status: All without HTN at baseline; Excluded those with diagnosis of hypertension at baseline; those who did not provide dietary information | Exposure: Total red meat (unprocessed and processed meats, including bacon, hot dogs, hamburgers, beef, pork, lamb); 1 serving (amount NR); Comparator: Continuous (1 svg/d substitution) Seafood (dark meat fish, other fish, shrimp, lobster, and canned tuna); Assessment methods and timing:; - FFQ at baseline and every 4y; Outcome assessment methods and timing:; - HTN self-reported on annual questionnaires; - 20-26y | [underlined: Incident HTN] by 1 svg substitution, HR (95% CI); Seafood for meat; NHS: Data NR (figure only), P=NS; NHS II: Data NR (figure only), P=NS; HPFS: 1.12 (1.05, 1.18) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (fruits and vegetables, whole grains, SSB, artificially sweetened beverages), total energy intake; - Other: family history of HTN; post-menopausal status; oral contraceptive use (in NHS II); use of non-narcotic analgesic use; change in weight; Limitations:; - Did not account for key confounders: Socioeconomic position; - Outcome was self-reported; - No preregistered data analysis plan; Funding:; AHA
Haring, 2014^38^; PCS, United States, ARIC; Analytic N = 12,066; Participant characteristics:; - Age: ~53.8 (5.7)y; 45-64y; - Female: 56%; - Race and/or ethnicity: 77% White; 23% Black; - SEP: 79% high school graduates; - BMI: 27.1 kg/m^2^; - Health Status: 29% HTN; ~26% current smoker; Excluded participants with self-reported diabetes, fasting blood glucose ≥126 mg/dL, non-fasting blood glucose ≥200 mg/dL or use of diabetes medication, a history of myocardial infarction, stroke, heart failure, coronary bypass surgery, angioplasty or with missing data on covariates of interest, implausible energy intake or incomplete dietary information | Exposure: Processed red meat: details NR; Red meat: unprocessed, details NR; Comparator: Continuous (1 svg/d substitution); - Fish/seafood: details NR; Assessment methods and timing:; - FFQ at baseline and ~6y follow-up (cumulative average); Outcome assessment methods and timing:; - CHD (definite or probable MI, or CHD death) adjudicated using information from study visits, yearly telephone follow-up calls, review of hospital discharge lists and medical charts, death certificates, next-of-kin interviews, and physician-completed questionnaires; - 22y | [underlined: CHD] by 1 svg/d substitution, HR (95% CI); Fish/seafood for processed meat: 0.98 (0.74, 1.15); Fish/seafood for red meat: 0.86 (0.65, 1.13) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (all the food items in the table, fiber intake), total energy intake; - Other: study center, systolic blood pressure, use of antihypertensive and/or lipid lowering medication, HDL, total cholesterol, carbohydrate intake, magnesium intake; Limitations:; - No preregistered data analysis plan; Funding:; NHLBI/NIH; German Research Foundation; University of Wurzburg
Key, 2019^56^; PCS, Multiple (9 European countries), EPIC; Analytic N = 409,885; Participant characteristics:; - Age: 52.7 (10.3)y in men, 51.3 (9.8)y in women; - Female: 74%; - Race and/or ethnicity: NR; - SEP: 46% vocational or university education; - BMI: 26.6 (3.7) kg/m^2^ in men, 25.0 (4.4) kg/m^2^ in women; - Health Status: 17% HTN, 14% hyperlipidemia; Excluded those with missing data, top or bottom 1% of ratio of energy intake to energy requirement, MI or stroke | Exposure: Red meat: unprocessed (including beef, veal, pork, lamb, mutton, goat, horse, hamburger, meatballs, minced meat) and processed meat (meat products, including poultry, preserved by methods other than freezing, such as salting with or without nitrites, smoking, marinating, air drying, or heating, and including ham, bacon, sausages, blood sausages, chicken sausage, meat cuts, liver paté, salami, bologna, tinned meat, luncheon meat, corned beef and black pudding); Comparator: Continuous (100 kcal/d substitution); - White fish: details NR; - Fatty fish: details NR; Assessment methods and timing:; - FFQ at baseline (country-specific); Outcome assessment methods and timing:; - Ischemic heart disease (IHD): composite of first non-fatal MI or death from IHD from hospital registries and self-reports confirmed with medical records; mortality registries or follow-up with next of kin; - 12.6y | [underlined: IHD] by 100 kcal/d substitution, HR (95% CI); White fish for red and processed meat: 1.00 (0.78, 1.26); Fatty fish for red and processed meat: 0.81 (0.69, 0.95) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (employment status, education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit and vegetable intake, sugar, fiber), total energy intake; - Other: history of DM, hypertension, hyperlipidemia, EPIC center, other foods as appropriate (poultry meat, white fish, fatty fish, milk, yogurt, cheese, and eggs); Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only; - Some variations in the ascertainment and validation of the endpoint; - No preregistered data analysis plan; Funding:; UK Medical Research Council; Cancer Research UK; Wellcome Trust; European Union Framework 7; European Research Council; British Heart Foundation; UK National Institute of Health Research; European Commission; International Agency for Research on Cancer
Nielsen, 2021^71^; PCS, Denmark, Danish Diet, Cancer and Health; Analytic N = 54,229; Participant characteristics:; - Age: 56 (4)y; 50-64y; - Female: 53%; - Race and/or ethnicity: NR; - SEP: 62% with medium or long tertiary education; - BMI: 43% with 18.5-25 kg/m^2^; 56% >25 kg/m^2^; - Health Status: 2% T2D; 16% HTN; 7% hypercholesterolemia; Excluded those with previous diagnoses of cancer or CVD (myocardial infarction or stroke) and missing information on covariates | Exposure: Total red meat: unprocessed and processed red meat; Unprocessed red meat: cooked and uncooked red meat, including beef, veal, pork, lamb and offal Processed red meat: all red meat that had undergone processing such as smoking, salting or curing, including sausages, salami, smoked or cooked ham, bacon and liver pate; Comparator: Continuous (150 g/wk substitution); - Fish: all types of fish and shellfish, such as raw fish, cold cuts, roe, shellfish and prepared/cooked fish; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD mortality from record linkage to the Danish National Patient Register and the Cause of Death Register; - 16.1y | [underlined: CVD mortality] by 150 g/wk substitution, HR (95% CI); Fish for total red meat: 1.01(0.96, 1.05); Fish for unprocessed red meat: 1.03 (1.00, 1.08); Fish for processed red meat: 0.97 (0.92, 1.02) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit and vegetable consumption), total energy intake; - Other: hypercholesteraemia, diabetes, HTN; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Diet measured at baseline only; - No preregistered data analysis plan; Funding:; Danish Cancer Society
Sun, 2021^80^; PCS, United States, Women’s Health Initiative; Analytic N = 102,521; Participant characteristics:; - Age: 62 (7)y; 50-79y; - Female: 100%; - Race and/or ethnicity: 82% White; 9% Black; ~4% Hispanic; ~5% Other/Missing; - SEP: 32% high school or less, 27% some college, 40% college or higher; 37% annual income >$50K; - BMI: ~27 (5) kg/m^2^; - Health Status: 48% family history of heart attack; 36% family history of stroke; Excluded those with missing data, energy intake <600 or >5000 kcal/d, CVD or cancer at baseline | Exposure: Total red meat: unprocessed (beef, pork, veal, lamb, and game) and processed (franks, sausages, luncheon meats); computed into ounce equivalent according to protein content (1 oz meat = 1 oz equivalent of protein food); Comparator: Continuous (2 oz-eq/d substitution); - Fish/shellfish: fish and other seafood; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD mortality (included deaths from atherosclerotic cardiac, definite coronary heart disease, possible coronary heart disease, cerebrovascular disease, pulmonary embolism, and other or unknown cardiovascular disease) from death certificates, medical records, autopsy reports, or linkage to National Death Index; - 18.1y | [underlined: CVD mortality] by 2 oz-eq/d substitution, HR (95% CI); Fish for total red meat: data NR (figure only), P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education, income), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, whole grains, SSB, and other protein sources), total energy intake; - Other: hormone use; family history of heart attack/stroke; Limitations:; - Exposure measured at baseline only; - Data not provided beyond figure; - No preregistered data analysis plan; Funding:; NHLBI
Thao, 2023^81^; PCS, France, E3N; Analytic N = 45,771; Participant characteristics:; - Age: 51.8 (6.3)y; 40-65y; - Female: 100%; - Race and/or ethnicity: NR; - SEP: 36% university education; - BMI: 22.9 (3.2) kg/m^2^; - Health Status: 6% history of CVD; Excluded those with HTN, CVD, stroke, or myocardial infarction; missing dietary data or reporting no meat/fish intake; <1000 or >4000 kcal/d | Exposure: Processed red meat: sausage, ham, charcuterie, and pâté; Comparator: Continuous (150 g/wk substitution); - Fatty fish: salmon, sardines, trout and mackerel; - Lean fish: cod, sole, bass, ling, ray, whiting and haddock; Assessment methods and timing:; - FFQ at baseline and 12y follow-up (only baseline used in main analysis; follow-up used in sensitivity analyses); Outcome assessment methods and timing:; - HTN from self-report of date of diagnosis and use of antihypertensive treatments; validated with medication reimbursement; - 18.3y | [underlined: Incident HTN] by 150 g/wk substitution, HR (95% CI); Fatty fish for processed red meat: 0.85 (0.79, 0.91); Lean fish for processed red meat: 1.04 (1.00, 1.07); Data also provided stratified by BMI, smoking status, and history of diabetes; Secondary analysis also conducted using second FFQ | Model adjustments:; - Key confounders: Sex, age (at menopause), socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (SSB intake), total energy intake; - Other: family history of CVD and prevalent diabetes; use of menopausal hormone therapy; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - No preregistered data analysis plan; Funding:; Mutuelle Générale de l’Education Nationale; European Community; French League against Cancer; Gustave Roussy Institute; French Institute of Health and Medical Research; French Research Agency
van den Brandt, 2019^57^; NCC, The Netherlands, The Netherlands Cohort Study; Analytic N = 8823 deaths and 3202; subcohort members; Participant characteristics:; - Age: 61y; 55-69y; - Female: 60%; - Race and/or ethnicity: NR; - SEP: 16% university or higher vocational education; - BMI: ~25 kg/m^2^; - Health Status: ~25% HTN; ~3% T2D; Excluded those with a history of cancer (excluding skin cancer) or CVD (myocardial infarction, angina pectoris, stroke) at baseline, incomplete or inconsistent dietary data, or missing on confounders | Exposure: Processed meat: meat items that have undergone some form of preservation (mostly treatment with nitrite salt, sometimes smoked or fermented); included ham, bacon, smoked beef or pork loin roll, and other sliced cold meats (e.g., sausages); mainly referred to processed red meat, may contain small amounts of processed white meat (poultry) as in sausages; Comparator: Continuous (50 g/d substitution); - Fish: details NR; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD mortality determined from linkage with the Dutch Central Bureau of Genealogy and Statistics Netherlands; - 10y | [underlined: CVD mortality] by 50 g/d substitution, HR (95% CI); Fish for processed meat: 1.07 (0.80, 1.42) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit and vegetable intake), total energy intake; - Other: diabetes, HTN, use of nutritional supplements; postmenopausal HRT in women; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only; - No preregistered data analysis plan; Funding:; NR
Venø, 2018^82^; PCS, Denmark, Danish Diet, Cancer and Health; Analytic N = 55,338; Participant characteristics:; - Age: 56.1y; 50-64y; - Female: 52%; - Race and/or ethnicity: NR; - SEP: 21% with >10y schooling, 46% with 8-10y, 33% with <7y; - BMI: 25.5 kg/m^2^; - Health Status: 16% HTN, 7% hypercholesterolemia; Excluded those with missing data; cancer or stroke | Exposure: Processed red meat: red meat that had undergone smoking, salting or curing Unprocessed red meat: details NR; Comparator: Continuous (150 g/wk substitution); - Total fish: lean and fatty fish combined; - Lean fish: defined by a low content of n-3 PUFA (≤1 g/100 g); - Fatty fish: defined by a high content of n-3 PUFA (>1 g/100 g); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Ischemic stroke (subtypes included large artery atherosclerosis, cardioembolism, small-vessel occlusion, stroke of other etiology, and stroke of undetermined etiology) from Danish National Patient Register; - 13.5y | [underlined: Total ischemic stroke] by 150 g/wk; substitution, HR (95% CI); Total fish for processed red meat: 0.97 (0.91, 1.02); Lean fish for processed red meat: 0.98 (0.91, 1.06); Fatty fish for processed red meat: 0.95 (0.87, 1.03); Total fish for unprocessed red meat: 0.97 (0.93, 1.02); Lean fish for unprocessed red meat: 0.99 (0.92, 1.06); Fatty fish for unprocessed red meat: 0.95 (0.88, 1.04); Results also provided for ischemic stroke subtypes | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, total energy intake; - Other: hypercholesterolemia, diabetes mellitus, HTN, atrial fibrillation/atrial flutter; Limitations:; - Did not account for key confounders: Race and/or ethnicity, diet quality; - Did not clearly define all dietary exposures analyzed; - Exposure measured at baseline only; - No preregistered data analysis plan; Funding:; Danish Heart Foundation;; Danish Cancer Society
Wang, 2022^84^; PCS, UK, UK Biobank; Analytic N = 180642; Participant characteristics:; - Age: 55.7 (7.9)y; 40-69y; - Female: 56%; - Race and/or ethnicity: 95% White (all European descent); - SEP: ~1.7 Townsend deprivation index; 55% household income ≥31K£; - BMI: ~27 kg/m^2^; - Health Status: 16% on antihypertensive medication, 13% on cholesterol lowering medication; Excluded those with cancer or CVD, missing dietary data at baseline, <500 or >3500 kcal/d | Exposure: Unprocessed red meat: beef, lamb/mutton, and pork (excluding processed meats); Comparator: Continuous (1 svg/d substitution); - Fish: details NR, measured in frequency per week; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Mortality (CVD, CHD, and stroke) from death certificate; - 8.6y | [underlined: CVD mortality] by 1 svg/d substitution, HR (95% CI); Fish for red meat: 1.00 (0.94, 1.07); [underlined: CHD mortality] by 1 svg/d substitution, HR (95% CI); Fish for red meat: 0.96 (0.87, 1.06); [underlined: Stroke mortality] by 1 svg/d substitution, HR (95% CI); Fish for red meat: 0.99 (0.86, 1.14) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (household income, deprivation index), physical activity, anthropometry, smoking, alcohol, total energy intake; - Other: UK Biobank assessment center; Limitations:; - Did not account for key confounders: Diet quality; - Only baseline exposure measurements used in primary analysis; - Did not account for loss to follow-up; - No preregistered data analysis plan; Funding:; NHLBI; NIDDK; Fogarty International Center
Wang, 2024^83^; PCS, United States, Million Veteran; Program; Analytic N = 148,506; Participant characteristics:; - Age: 61y; - Female: 12%; - Race and/or ethnicity: 81% White; 13% African American; 7% Hispanic; 1% Asian; 1% American Indian; 3% Other; - SEP: 50% college or above; 58% married; 33% family income ≥$60K/y; - BMI: ~28 kg/m^2^; - Health Status: 38% HTN; 35% hypercholesterolemia; Excluded those with missing data, diabetes, cancer, CVD, energy intake <400 or ≥4000 kcal/d (women) or <450 or ≥4500 kcal/d (men) | Exposure: Red meat: unprocessed and processed red meat; Unprocessed red meat: beef, pork, and lamb as a main dish, sandwich, or mixed dish (3oz svg); hamburger patty; Processed red meat: bacon, hot dogs, sausage, salami, bologna, and other processed red meats; Comparator: Continuous (0.5 svg/d substitution); - Fish: details NR; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and nonfatal, including myocardial infarction and acute ischemic stroke) from National Death Index and validated highthroughput phenotyping algorithm; - 3.8y | [underlined: Incident CVD] by 0.5 svg/d substitution, RR (95% CI); Fish for red meat: data NR (figure only), P=NS; Fish for unprocessed red meat: P=NS; Fish for processed red meat: P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education, income, marriage status), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, nuts, yogurt, whole grain, legume, skim milk, eggs, nonskin chicken, fish, SSB), total energy intake; - Other: history of HTN or hypercholesterolemia; Limitations:; - Exposure measured at baseline only; - Inadequate adjustment for missing data; - No preregistered data analysis plan; Funding:; U.S. Department of Veterans Affairs
Würtz, 2016b^86^; PCS, Denmark, Danish Diet, Cancer and Health; Analytic N = 55,171 (29,142 women; 26,029 men); Participant characteristics:; - Age: ~56y; 50-64y; - Female: 53%; - Race and/or ethnicity: NR, 100% born in Denmark; - SEP: 32% <8y education; - BMI: ~26 (21-33) kg/m^2^; - Health Status: 2% T2D; 16% HTN; 7% hypercholesterolemia; Excluded those with cancer or MI at baseline, missing baseline data | Exposure: Red meat: unprocessed and processed red meat; Unprocessed red meat: fresh and minced beef, veal, pork, and lamb; Fatty unprocessed red meat: >10g fat per 100g Processed red meat: red meat items processed via smoking, salting or curing (sausages, salami, smoked or cooked ham, cold cuts, bacon, liver pate); Comparator: Continuous (150 g/wk substitution); - Total fish: unprocessed and processed fish and shellfish; - Lean fish: ≤1g omega-3 PUFA per 100g (lean white fish, canned tuna and sardines, shellfish, cod roe); - Fatty fish: >1g omega-3 PUFA per 100g (darker fish such as salmon, trout, herring, fresh and canned mackerel, lumpfish roe); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Myocardial infarction (fatal and nonfatal) from Danish National Patient Register and in the Danish Cause of Death Register; - 13.5y | [underlined: MI] per 150 g/wk substitution, HR (95% CI); Fish for red meat; All: 0.96 (0.93, 1.00); Women: 0.90 (0.82, 0.99); Men: 0.98 (0.94, 1.02); Fish for unprocessed red meat; All: 0.97 (0.93, 1.02); Women: 0.88 (0.80, 0.98); Men: 0.99 (0.95, 1.04); Fish for processed red meat; All: 0.95 (0.90, 1.00); Women: 0.94 (0.83, 1.07); Men: 0.95 (0.90, 1.00); Lean fish for red meat; All: 1.00 (0.95, 1.07); Women: 1.00 (0.88, 1.14); Men: 1.00 (0.94, 1.07); Fatty fish for red meat; All: 0.91 (0.85, 0.98); Women: 0.78 (0.66, 0.91); Men: 0.95 (0.88, 1.03) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit, vegetables, sweets, soft drinks, lean and fatty dairy products, fatty potatoes, refined and whole grain cereals, nuts), total energy intake; - Other: menopausal status; HRT use; HTN; Hypercholesterolemia; T2D; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Diet measured at baseline only; - No preregistered data analysis plan; Funding:; Danish Council for Strategic Research; Aarhus University; Danish Cancer Society
Zhong, 2021^87^; PCS, United States, Multiple cohorts; (ARIC, CARDIA, CHS, FHS, FOS, MESA); Analytic N = 29,682; Participant characteristics:; - Age: 53.7 (15.7)y; - Female: 56%; - Race and/or ethnicity: 69% nonHispanic White; 24% non-Hispanic Black; 4.5% Hispanic; 2% Chinese; <1% Other; - SEP: 53% some college or more; 47% high school or less; - BMI: NR; - Health Status: Generally healthy; Excluded those with CVD at baseline, missing data, or <500 or >6000 kcal/d | Exposure: Processed meat: 1 svg equivalent to two slices of bacon, two small links of sausage or one hot dog; Unprocessed red meat: details NR; 1 svg equivalent to 85.05 g (i.e., 3 oz); Comparator: Continuous (1 svg/wk substitution); - Fish: details NR; 1 svg equivalent to 85.05 g (i.e., 3 oz); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and non-fatal CHD, fatal and nonfatal stroke, fatal and non-fatal heart failure, and other CVD deaths) from medical records and/or autopsy data; - 19y | [underlined: Incident CVD] by 1 svg/wk substitution, HR (95% CI); Fish for processed meat: 0.96 (0.94, 0.99), P<0.01; Fish for unprocessed red meat: 0.99 (0.98, 1.00); Results also provided for 1 svg/d substitution, as well as absolute risk difference. | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, smoking, alcohol, diet quality (AHEI), total energy intake; - Other: cohort; other foods (eggs, processed meat, unprocessed red meat, poultry, fish, nuts, legumes, whole grains); hormone therapy; Limitations:; - Did not account for key confounders: Anthropometry; - Exposure measured at baseline only; - Inadequate information on amount of missingness; - No preregistered data analysis plan; Funding:; AHA Strategically Focused Research Network; NHLBI; Northwestern University Feinberg School of Medicine
Zhu, 2022^88^; PCS, Multiple (Finland, UK, New Zealand, Australia), Secondary analysis of PREVIEW trial; Analytic N = 668; Participant characteristics:; - Age: 57y; 26-70y; - Female: 69%; - Race and/or ethnicity: 86% Caucasian; 3% Black; 3% Asian; 7% Other; 1% Arabic; - SEP: NR; - BMI: 29.5 kg/m^2^; - Health Status: 100% prediabetes; Excluded those <25 or >70y; BMI <25 kg/m^2^; without prediabetes based on ADA 2022 criteria; type 1 or type 2 diabetes; missing dietary data; <600 or >3500 kcal/d for women, or <800 or >4200 kcal/day for men | Exposure: Processed meat: frankfurters, sausage, bacon, corned beef, cured ham and luncheon meat made from beef, pork, poultry; Comparator: Continuous (60-72 kcal/d substitution); - Fish and seafood: fatty fish, fish products, low-fat fish, canned fatty fish, canned low-fat fish, seafoods, crustaceans including lobster and shrimps; Assessment methods and timing:; - 4d diet records at 25, 52, 104, and 156wk (cumulative average); Outcome assessment methods and timing:; - TG from fasting blood collection at 8, 26, 52, 104, and 156wk; - 3y | [underlined: TG (mmol/L)] by 60-72 kcal/d substitution, Mean change per year (95% CI); Fish and seafood for processed meat: −0.06 (0.09, −0.02), P=0.004 | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, alcohol, diet quality (intake of animal-based food, grains, legumes, nuts, fruit, vegetables, and sugar), total energy intake; - Other: intervention center, yearly weight change; Limitations:; - Did not account for key confounders: Socioeconomic position, smoking; - No preregistered data analysis plan; Funding:; EU framework programme 7; National Health and Medical Research Council; The Glycemic Index Foundation Australia; The New Zealand Health Research Council; University of Auckland Faculty Research Development Fund; Danish Agriculture & Food Council; Danish Meat and Research Institute; National Institute for Health Research Biomedical Research Centre; Engineering and Physical Sciences Research Council

a Abbreviations: AHEI: Alternative Healthy Eating Index; BMI: body mass index; CABG: coronary artery bypass grafting; CHD: coronary heart disease; CHO: carbohydrate; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DBP: diastolic blood pressure; dL: deciliter(s); DM: diabetes mellitus; eq: equivalent; FFQ: food frequency questionnaire; HDL: high-density lipoprotein cholesterol; HTN: hypertension; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); m: meter(s); L: liter(s); LDL: low-density lipoprotein cholesterol; MI: myocardial infarction; mmHg: millimetre of mercury; mmol: millimole(s); mo: month(s); MUFA: monounsaturated fatty acids; NCC: nested case control; NR: not reported; NS: not significant; OR: odds ratio; oz: ounce(s); P: p-value; PCS: prospective cohort study; PUFA: polyunsaturated fatty acids; RCT: randomized controlled trial; RR: risk ratio; SBP: systolic blood pressure; SD: standard deviation; SEM: standard error of the mean; SFA: saturated fatty acids; SEP: socioeconomic position; SSB: sugar-sweetened beverages; svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; TG: triglycerides; wk: week(s); y: year(s)

Table 62 Risk of bias for observational studies examining red meat compared to fish and seafood in adults and older adults and risk of cardiovascular disease^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Al-Shaar, 2020^53^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bernstein, 2010^34^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bernstein, 2012^54^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Borgi, 2015^59^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Haring, 2014^38^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Key, 2019^56^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Nielsen, 2021^71^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Sun, 2021^80^ | LOW* | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Thao, 2023^81^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
van den Brandt, 2019^57^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Venø, 2018^82^ | HIGH | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Wang, 2022^84^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Wang, 2024^83^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Würtz, 2016b^86^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Zhong, 2021^87^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zhu, 2022^88^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 63 Evidence examining the relationship between substituting one form of dairy with another form^a^

Study and Participant Characteristics | Intervention/Exposure and Comparator | Results | Methodological Considerations
Al-Shaar, 2020^53^; PCS, United States, HPFS; Analytic N = 43,272; Participant characteristics:; - Age: 53 (9.5)y; 40-75y; - Female: 0%; - Race and/or ethnicity: 95% White; “mostly non-Hispanic”; - SEP: All health professionals; - BMI: 25.5 (3.3) kg/m^2^; - Health Status: 20% history of HTN, 10% high cholesterol; Excluded those with missing data; energy intake <800 or >4200 kcal/d; history of cancer, myocardial infarction, angina, CABG, or stroke | Exposure: Total red meat: processed and unprocessed red meat; Unprocessed red meat: hamburger (lean or extra lean), regular hamburgers, beef, pork, or lamb as a sandwich or main or mixed dish (e.g., stew, casserole, lasagna, frozen dinners, etc). Processed red meat: beef or pork hotdogs, bacon, salami, bologna, other processed meat sandwiches, other processed meats (e.g., sausages, kielbasa, etc); Comparator: Continuous (1 svg/d substitution); - Eggs: regular eggs including yolk; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - CHD (acute non-fatal MI or fatal CHD) from physician review of medical records, telephone interview of supplemental information, death certificate; - 30y | [underlined: CHD] by 1 svg/d substitution, HR (95% CI); Eggs for total red meat: 0.90 (0.81, 1.01), P=0.07; Eggs for unprocessed red meat: 0.93 (0.82, 1.05), P=0.26; Eggs for processed red meat: 0.87 (0.76, 0.99), P=0.04 | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (marital status, living arrangement, profession, work status), physical activity, anthropometry, smoking, alcohol, diet quality (intakes of poultry, fish, egg, high fat dairy, low fat dairy, nuts, legumes, soy, whole grains, fruits, vegetables), total energy intake; - Other: multivitamin and/or aspirin use; family history of CHD or stroke; intake of coffee; glycemic index; Limitations:; - No preregistered data analysis plan; Funding: NIH
Bernstein, 2012^54^; PCS, United States, NHS, HPFS; Analytic N = 127,160; Participant characteristics:; - Age: NHS ~57y, 30-55y; HPFS ~62y, 40-75y; - Female: 66%; - Race and/or ethnicity: Mostly White; - SEP: All nurses/health professionals; - BMI: ~26 kg/m^2^; - Health Status: ~33% high BP (HPFS & NHS); ~38% high cholesterol (HPFS), 35% high cholesterol (NHS); Excluded participants diagnosed with cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of percutaneous coronary intervention or coronary artery bypass grafting) at baseline; excessive missing data on FFQ; implausible energy intake | Exposure: Red meat: unprocessed red meat (hamburger, beef, pork, and lamb), processed red meat (beef hot dog, processed meats such as bologna and salami, and bacon); Comparator: Continuous (1 svg/d substitution) Eggs: 1 svg = 1 egg; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - Stroke [ischemic (thrombotic, embolic, or unspecified non-hemorrhagic), hemorrhagic, or of unknown type] from medical records, autopsy report, death certificate, or report by next-of-kin; - 22-26 y | [underlined: Stroke] by 1 svg/d substitution, HR (95% CI); Eggs for red meat: Data NR (figure only), P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, fruit and vegetables, trans fat, other protein sources), total energy intake; - Other: time period, parental history of MI (<60y), menopausal status (women), multivitamin use, vitamin E supplement use, aspirin use; Limitations:; - Did not account for key confounders: Socioeconomic position; - Unclear how many participants were excluded for exposure missingness vs. previous diagnosis of a condition; - No preregistered data analysis plan; Funding: NIH; Harvard Human Nutrition Program
Haring, 2014^38^; PCS, United States, ARIC; Analytic N = 12,066; Participant characteristics:; - Age: ~53.8 (5.7)y; 45-64y; - Female: 56%; - Race and/or ethnicity: 77% White; 23% Black; - SEP: 79% high school graduates; - BMI: 27.1 kg/m^2^; - Health Status: 29% HTN; ~26% current smoker; Excluded participants with self-reported diabetes, fasting blood glucose ≥126 mg/dL, non-fasting blood glucose ≥200 mg/dL or use of diabetes medication, a history of myocardial infarction, stroke, heart failure, coronary bypass surgery, angioplasty or with missing data on covariates of interest, implausible energy intake or incomplete dietary information | Exposure: Processed red meat: details NR; Red meat: unprocessed, details NR; - Also examined poultry (details NR); Comparator: Continuous (1 svg/d substitution); - Eggs: details NR; Assessment methods and timing:; - FFQ at baseline and ~6y follow-up (cumulative average); Outcome assessment methods and timing:; - CHD (definite or probable MI, or CHD death) adjudicated using information from study visits, yearly telephone follow-up calls, review of hospital discharge lists and medical charts, death certificates, next-of-kin interviews, and physician-completed questionnaires; - 22y | [underlined: CHD] by 1 svg/d substitution, HR (95% CI); Eggs for processed meat: 0.92 (0.74, 1.15); Eggs for red meat: 0.81 (0.63, 1.05); Eggs for poultry: 0.99 (0.77, 1.29) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (all the food items in the table, fiber intake), total energy intake; - Other: study center, systolic blood pressure, use of antihypertensive and/or lipid lowering medication, HDL, total cholesterol, carbohydrate intake, magnesium intake; Limitations:; - No preregistered data analysis plan; Funding: NHLBI/NIH; German Research Foundation; University of Wurzburg
Key, 2019^56^; PCS, Multiple (9 European countries), EPIC; Analytic N = 409,885; Participant characteristics:; - Age: 52.7 (10.3)y in men, 51.3 (9.8)y in women; - Female: 74%; - Race and/or ethnicity: NR; - SEP: 46% vocational or university education; - BMI: 26.6 (3.7) kg/m^2^ in men, 25.0 (4.4) kg/m^2^ in women; - Health Status: 17% HTN, 14% hyperlipidemia; Excluded those with missing data, top or bottom 1% of ratio of energy intake to energy requirement, MI or stroke | Exposure: Red meat: unprocessed (including beef, veal, pork, lamb, mutton, goat, horse, hamburger, meatballs, minced meat) and processed meat (meat products, including poultry, preserved by methods other than freezing, such as salting with or without nitrites, smoking, marinating, air drying, or heating, and including ham, bacon, sausages, blood sausages, chicken sausage, meat cuts, liver paté, salami, bologna, tinned meat, luncheon meat, corned beef and black pudding); Comparator: Continuous (100 kcal/d substitution); - Eggs: treated as single item; Assessment methods and timing:; - FFQ at baseline (country-specific); Outcome assessment methods and timing:; - Ischemic heart disease (IHD): composite of first non-fatal MI or death from IHD from hospital registries and self-reports confirmed with medical records; mortality registries or follow-up with next of kin; - 12.6y | [underlined: IHD] by 100 kcal/d substitution, HR (95% CI); Eggs for red and processed meat: 0.76 (0.62, 0.92) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (employment status, education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit and vegetable intake, sugar, fiber), total energy intake; - Other: history of DM, hypertension, hyperlipidemia, EPIC center, other foods as appropriate (poultry meat, white fish, fatty fish, milk, yogurt, cheese, and eggs); Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only; - Some variations in the ascertainment and validation of the endpoint; - No preregistered data analysis plan; Funding:; UK Medical Research Council; Cancer Research UK; Wellcome Trust; European Union Framework 7; European Research Council; British Heart Foundation; UK National Institute of Health Research; European Commission; International Agency for Research on Cancer
Thao, 2023^81^; PCS, France, E3N; Analytic N = 45,771; Participant characteristics:; - Age: 51.8 (6.3)y; 40-65y; - Female: 100%; - Race and/or ethnicity: NR; - SEP: 36% university education; - BMI: 22.9 (3.2) kg/m^2^; - Health Status: 6% history of CVD; Excluded those with HTN, CVD, stroke, or myocardial infarction; missing dietary data or reporting no meat/fish intake; <1000 or >4000 kcal/d | Exposure: Processed red meat: sausage, ham, charcuterie, and pâté; Comparator: Continuous (150 g/wk substitution); - Eggs: details NR; Assessment methods and timing:; - FFQ at baseline and 12y follow-up (only baseline used in main analysis; follow-up used in sensitivity analyses); Outcome assessment methods and timing:; - HTN from self-report of date of diagnosis and use of antihypertensive treatments; validated with medication reimbursement; - 18.3y | [underlined: Incident HTN] by 150 g/wk substitution, HR (95% CI); Eggs for processed red meat: 0.98 (0.95, 1.01); Data also provided stratified by BMI, smoking status, and history of diabetes; Secondary analysis also conducted using second FFQ | Model adjustments:; - Key confounders: Sex, age (at menopause), socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (SSB intake), total energy intake; - Other: family history of CVD and prevalent diabetes; use of menopausal hormone therapy; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - No preregistered data analysis plan; Funding:; Mutuelle Générale de l’Education Nationale; European Community; French League against Cancer; Gustave Roussy Institute; French Institute of Health and Medical Research; French Research Agency
van den Brandt, 2019^57^; NCC, The Netherlands, The Netherlands Cohort Study; Analytic N = 8823 deaths and 3202 subcohort members; Participant characteristics:; - Age: 61y; 55-69y; - Female: 60%; - Race and/or ethnicity: NR; - SEP: 16% university or higher vocational education; - BMI: ~25 kg/m^2^; - Health Status: ~25% HTN; ~3% T2D; Excluded those with a history of cancer (excluding skin cancer) or CVD (myocardial infarction, angina pectoris, stroke) at baseline, incomplete or inconsistent dietary data, or missing on confounders | Exposure: Processed meat: meat items that have undergone some form of preservation (mostly treatment with nitrite salt, sometimes smoked or fermented); included ham, bacon, smoked beef or pork loin roll, and other sliced cold meats (e.g., sausages); mainly referred to processed red meat, may contain small amounts of processed white meat (poultry) as in sausages; Comparator: Continuous (50 g/d substitution); - Eggs: details NR; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD mortality determined from linkage with the Dutch Central Bureau of Genealogy and Statistics Netherlands; - 10y | [underlined: CVD mortality] by 50 g/d substitution, HR (95% CI); Eggs for processed meat: 0.73 (0.52, 1.03) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit and vegetable intake), total energy intake; - Other: diabetes, HTN, use of nutritional supplements; postmenopausal HRT in women; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only; - No preregistered data analysis plan; Funding: NR
Wang, 2024^83^; PCS, United States, Million Veteran Program; Analytic N = 148,506; Participant characteristics:; - Age: 61y; - Female: 12%; - Race and/or ethnicity: 81% White; 13% African American; 7% Hispanic; 1% Asian; 1% American Indian; 3% Other; - SEP: 50% college or above; 58% married; 33% family income ≥$60K/y; - BMI: ~28 kg/m^2^; - Health Status: 38% HTN; 35% hypercholesterolemia; Excluded those with missing data, diabetes, cancer, CVD, energy intake <400 or ≥4000 kcal/d (women) or <450 or ≥4500 kcal/d (men) | Exposure: Red meat: unprocessed and processed red meat; Unprocessed red meat: beef, pork, and lamb as a main dish, sandwich, or mixed dish (3oz svg); hamburger patty; Processed red meat: bacon, hot dogs, sausage, salami, bologna, and other processed red meats; Comparator: Continuous (0.5 svg/d substitution); - Eggs: details NR; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and nonfatal, including myocardial infarction and acute ischemic stroke) from National Death Index and validated highthroughput phenotyping algorithm; - 3.8y | [underlined: Incident CVD] by 0.5 svg/d substitution, RR (95% CI); Eggs for red meat: data NR (figure only), P=NS; Eggs for unprocessed red meat: P=NS; Eggs for processed red meat: P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education, income, marriage status), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, nuts, yogurt, whole grain, legume, skim milk, eggs, nonskin chicken, fish, SSB), total energy intake; - Other: history of HTN or hypercholesterolemia; Limitations:; - Exposure measured at baseline only; - Inadequate adjustment for missing data; - No preregistered data analysis plan; Funding: U.S. Department of Veterans Affairs
Zhong, 2021^87^; PCS, United States, Multiple cohorts (ARIC, CARDIA, CHS, FHS, FOS, MESA); Analytic N = 29,682; Participant characteristics:; - Age: 53.7 (15.7)y; - Female: 56%; - Race and/or ethnicity: 69% non-Hispanic White; 24% non-Hispanic Black; 4.5% Hispanic; 2% Chinese; <1% Other; - SEP: 53% some college or more; 47% high school or less; - BMI: NR; - Health Status: Generally healthy; Excluded those with CVD at baseline, missing data, or <500 or >6000 kcal/d | Exposure: Processed meat: 1 svg equivalent to two slices of bacon, two small links of sausage or one hot dog; Unprocessed red meat: details NR; 1 svg equivalent to 85.05 g (i.e., 3 oz); - Also examined poultry (details NR); Comparator: Continuous (1 svg/wk substitution); - Eggs: 1 svg equivalent to 1 whole egg; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and non-fatal CHD, fatal and nonfatal stroke, fatal and non-fatal heart failure, and other CVD deaths) from medical records and/or autopsy data; - 19y | [underlined: Incident CVD] by 1 svg/wk substitution, HR (95% CI); Processed meat for eggs: 1.01 (0.99, 1.03); Unprocessed red meat for eggs: 0.99 (0.97, 1.00), P<0.05; Poultry for eggs: 0.99 (0.97, 1.00); Results also provided for 1 svg/d substitution, as well as absolute risk difference. | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, smoking, alcohol, diet quality (AHEI), total energy intake; - Other: cohort; other foods (eggs, processed meat, unprocessed red meat, poultry, fish, nuts, legumes, whole grains); hormone therapy; Limitations:; - Did not account for key confounders: Anthropometry; - Exposure measured at baseline only; - Inadequate information on amount of missingness; - No preregistered data analysis plan; Funding: AHA Strategically Focused Research Network; NHLBI; Northwestern University Feinberg School of Medicine
Zhu, 2022^88^; PCS, Multiple (Finland, UK, New Zealand, Australia), Secondary analysis of PREVIEW trial; Analytic N = 668; Participant characteristics:; - Age: 57y; 26-70y; - Female: 69%; - Race and/or ethnicity: 86% Caucasian; 3% Black; 3% Asian; 7% Other; 1% Arabic; - SEP: NR; - BMI: 29.5 kg/m^2^; - Health Status: 100% prediabetes; Excluded those <25 or >70y; BMI <25 kg/m^2^; without prediabetes based on ADA 2022 criteria; type 1 or type 2 diabetes; missing dietary data; <600 or >3500 kcal/d for women, or <800 or >4200 kcal/day for men | Exposure: Processed meat: frankfurters, sausage, bacon, corned beef, cured ham and luncheon meat made from beef, pork, poultry; Comparator: Continuous (60-72 kcal/d substitution); - Eggs: eggs, egg products, egg dishes; Assessment methods and timing:; - 4d diet records at 25, 52, 104, and 156wk (cumulative average); Outcome assessment methods and timing:; - TG from fasting blood collection at 8, 26, 52, 104, and 156wk; - 3y | [underlined: TG (mmol/L)] by 60-72 kcal/d substitution, Mean change per year (95% CI); Eggs for processed meat: −0.02 (−0.08, 0.05), P=0.060 | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, alcohol, diet quality (intake of animal-based food, grains, legumes, nuts, fruit, vegetables, and sugar), total energy intake; - Other: intervention center, yearly weight change; Limitations:; - Did not account for key confounders: Socioeconomic position, smoking; - No preregistered data analysis plan; Funding:; EU framework programme 7; National Health and Medical Research Council; The Glycemic Index Foundation Australia; The New Zealand Health Research Council; University of Auckland Faculty Research Development Fund; Danish Agriculture & Food Council; Danish Meat and Research Institute; National Institute for Health Research Biomedical Research Centre; Engineering and Physical Sciences Research Council
Zhuang, 2021^89^; PCS, United States, NIH-AARP; Analytic N = 521120; Participant characteristics:; - Age: 62.2 (5)y; 50-71y; - Female: 41%; - Race and/or ethnicity: 92% nonHispanic White; 4% non-Hispanic Black; 4% Other/Missing; - SEP: 39% college graduate or higher; - BMI: ~27 (5) kg/m^2^; - Health Status: 23% HTN; 26% high cholesterol; 15% heart disease; 13% fair or poor health (definitions NR); Excluded those with missing data; <800 or >4,200 kcal/d for men and <600 or >3,500 kcal/d for women | Exposure: Red meat: unprocessed red meat (pork, beef, steak, liver, and hamburger) and processed red meat (bacon, hot dogs, cold cuts, ham, and sausage); - Also examined white meat/poultry: unprocessed white meat (turkey, chicken, ground poultry) and processed white meat (processed poultry components of turkey or chicken cold cuts); Comparator: Continuous (replacing half a whole egg with equivalent amount of other protein sources); - Half a whole egg = 25 g/d; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD mortality (included deaths from atherosclerotic cardiac, definite coronary heart disease, possible coronary heart disease, cerebrovascular disease, pulmonary embolism, and other or unknown cardiovascular disease) from linkage to National Death Index Plus; - 16y | [underlined: CVD mortality] by substitution for whole egg, HR (95% CI); Red meat: 0.96 (0.95, 0.98); Red meat (processed): 0.96 (0.94, 0.98); Red meat (unprocessed): 0.96 (0.95, 0.98); White meat/Poultry: 0.92 (0.91, 0.93); White meat/Poultry (processed): 0.95 (0.92, 0.97); White meat/Poultry (unprocessed): 0.92 (0.90, 0.93) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education, marital status), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, potatoes, whole grains, refined grains, coffee, SSB), total energy intake; - Other: usual activity at work; HTN; hypercholesterolemia; heart disease; stroke; diabetes; cancer; Limitations:; - Exposure measured at baseline only; Funding: National Key Research and Development Program of China

a Abbreviations: AHEI: Alternative Healthy Eating Index; BMI: body mass index; CABG: coronary artery bypass grafting; CHD: coronary heart disease; CHO: carbohydrate; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DBP: diastolic blood pressure; dL: deciliter(s); DM: diabetes mellitus; eq: equivalent; FFQ: food frequency questionnaire; HDL: high-density lipoprotein cholesterol; HTN: hypertension; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); m: meter(s); L: liter(s); LDL: low-density lipoprotein cholesterol; MI: myocardial infarction; mmHg: millimetre of mercury; mmol: millimole(s); mo: month(s); MUFA: monounsaturated fatty acids; NCC: nested case control; NR: not reported; NS: not significant; OR: odds ratio; oz: ounce(s); P: p-value; PCS: prospective cohort study; PUFA: polyunsaturated fatty acids; RCT: randomized controlled trial; RR: risk ratio; SBP: systolic blood pressure; SD: standard deviation; SEM: standard error of the mean; SFA: saturated fatty acids; SEP: socioeconomic position; SSB: sugar-sweetened beverages; svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; TG: triglycerides; wk: week(s); y: year(s)

Table 64 Risk of bias for observational studies examining red meat compared to eggs in adults and older adults and risk of cardiovascular disease^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall of bias
Al-Shaar, 2020^53^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bernstein, 2012^54^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Haring, 2014^38^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Key, 2019^56^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Thao, 2023^81^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
van den Brandt, 2019^57^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Wang, 2024^83^ | LOW* | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Zhong, 2021^87^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zhu, 2022^88^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zhuang, 2021^89^ | LOW* | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 65 Evidence examining the relationship between white meat compared to plant-based foods in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention/Exposure and Comparator | Results | Methodological Considerations
RANDOMIZED CONTROLLED TRIALS
Bergeron, 2019^58^; RCT-crossover, United States, APPROACH; (Animal and Plant Protein and Cardiovascular Health); Analytic N = 113; Adequately powered: No; Study aims: To test for differences in lipoprotein effects of diets in which the main source of protein is red meat compared with diets with similar total protein content derived from white meat (poultry) or plant protein sources, and to determine whether these effects were modified by high compared with low SFA intake.; Participant characteristics:; - Age: ~44 (12)y; 21-65y; - Female: 61%; - Race and/or ethnicity: 55% White, 20% Asian, 12% African American, 13% Other; - SEP: NR; - BMI: 26 (3.8) kg/m^2^; 42% with overweight, 16% with obesity; - Health Status: Majority normotensive; Excluded those using tobacco or recreational drugs; lipid-, glucose-, or blood-pressure-lowering medications, blood thinners, or hormones; unwillingness to consume all key study foods; weight loss >3% body weight in 3mo preceding study onset; history of coronary artery disease, diabetes, or other chronic disorder; BMI <20 or >35 kg/m^2^; blood pressure ≥150/90; fasting glucose ≥7 mmol/L, total and LDL cholesterol >95^th^% for sex and age; fasting triacylglycerol ≥5.65 mmol/L; unwillingness to refrain from use of vitamin supplements and alcoholic beverages during study | Intervention: Lean white meat: 8% energy from chicken and 4% energy from turkey; Comparator: Non-meat sources of protein: legumes, nuts, grains, isoflavone-free soy products; 2-3% of energy from SFA was derived from tropical oils and fats with the remainder from high-fat dairy; Other Comparator: Lean red meat: 11% energy from lean cuts of grain-finished beef and 1% energy from lean cuts of pork; Fish, seafood, and processed meats were excluded from all diets. For all diets, the remaining protein (~13% energy) was derived from eggs, dairy, and vegetable sources). Differences in SFA content between the high- and low-SFA arms were achieved primarily by using high-fat dairy products and butter, with only 2-3% energy from SFAs derived from lean red or white meat.; Duration: 4wk each (2-7wk washout) Compliance: Yes, using 24h urinary urea nitrogen and creatinine concentrations to monitor protein intake and weekly collection of menu checklists, grocery receipts, and reported deviations from dietary instructions; Outcome assessment methods and timing:; - LDL, HDL, TG, SBP, DBP; - Fasting blood collection and blood pressure at baseline and 4wk postbaseline | [underlined: LDL (mmol/L)], Mean difference (SE) at 4 wk; Red meat−Non-meat: 0.16 (0.03), P<0.0001; White meat−Non-meat: 0.16 (0.03), P<0.0001; [underlined: HDL (mmol/L)], Mean difference (SE) at 4wk; Red meat−Non-meat: 0.03 (0.01), P=0.007; White meat−Non-meat: 0.04 (0.01), P=0.001; [underlined: TG (mmol/L)], Mean difference (SE) at 4wk; Red meat−Non-meat: −0.03 (0.02), P=0.15; White meat−Non-meat: −0.03 (0.02), P=0.17; [underlined: SBP (mmHg)], Mean (SD) at 4 wk; Non-meat vs. white-meat vs. red meat, between groups: P=0.48; [underlined: DBP (mmHg)], Mean (SD) at 4 wk; Non-meat vs. white-meat vs. red meat, between groups: P=0.87 | Limitations:; - Not sufficiently powered; Funding: NIH
OBSERVATIONAL STUDIES
Bernstein, 2010^34^; PCS, United States, NHS; Analytic N = 84,136; Participant characteristics:; - Age: ~58y; 30-55y; - Female: 100%; - Race and/or ethnicity: Mostly White; - SEP: All nurses/health professionals; - BMI: ~26 kg/m^2^; - Health Status: 34% history of high BP; 36%history of high cholesterol; Excluded participants with incomplete FFQ; implausible TEI; previously diagnosed cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of coronary artery bypass grafting) | Exposure: Poultry: chicken with and without skin, chicken sandwich, and chicken/turkey hot dog; Comparator: Continuous (1 svg/d substitution); - Beans: including lentils, baked or dry; - Nuts: including peanuts, walnuts, other nuts; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - CHD (nonfatal MI and fatal CHD) from medical records, state vital records, National Death Index, postal system or report by kin; - 26y | [underlined: CHD] by 1 svg/d substitution, RR (95% CI); Beans for poultry: Data NR (figure only), P=NS; Nuts for poultry: Data NR (figure only), P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, trans fat), total energy intake; - Other: time period, menopausal status, parental history of early myocardial infarction, years of multivitamin use, vitamin E supplement use, aspirin use; Limitations:; - Did not account for key confounders: Socioeconomic position; - No preregistered data analysis plan; Funding: NIH; Unilever
Bernstein, 2012^54^; PCS, United States, NHS, HPFS; Analytic N = 127,160; Participant characteristics:; - Age: NHS ~57y, 30-55y; HPFS ~62y, 40-75y; - Female: 66%; - Race and/or ethnicity: Mostly White; - SEP: All nurses/health professionals; - BMI: ~26 kg/m^2^; - Health Status: ~33% high BP (HPFS & NHS); ~38% high cholesterol (HPFS), 35% high cholesterol (NHS); Excluded participants diagnosed with cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of percutaneous coronary intervention or coronary artery bypass grafting) at baseline; excessive missing data on FFQ; implausible energy intake | Exposure: Poultry: chicken with and without skin, chicken sandwich, and chicken/turkey hot dog; Comparator: Continuous (1 svg/d substitution); - Nuts: including peanuts, walnuts, other nuts; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - Stroke [ischemic (thrombotic, embolic, or unspecified non-hemorrhagic), hemorrhagic, or of unknown type] from medical records, autopsy report, death certificate, or report by next-of-kin; - 22-26 y | [underlined: Stroke] by 1 svg/d substitution, HR (95% CI) Nuts for poultry: 1.11 (0.90, 1.37) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, fruit and vegetables, trans fat, other protein sources), total energy intake; - Other: time period, parental history of MI (<60y), menopausal status (women), multivitamin use, vitamin E supplement use, aspirin use; Limitations:; - Did not account for key confounders: Socioeconomic position; - Unclear how many participants were excluded for exposure missingness vs. previous diagnosis of a condition; - No preregistered data analysis plan; Funding: NIH; Harvard Human Nutrition Program
Haring, 2014^38^; PCS, United States, ARIC; Analytic N = 12,066; Participant characteristics:; - Age: ~53.8 (5.7)y; 45-64y; - Female: 56%; - Race and/or ethnicity: 77% White; 23% Black; - SEP: 79% high school graduates; - BMI: 27.1 kg/m^2^; - Health Status: 29% HTN; ~26% current smoker; Excluded participants with self-reported diabetes, fasting blood glucose ≥126 mg/dL, non-fasting blood glucose ≥200 mg/dL or use of diabetes medication, a history of myocardial infarction, stroke, heart failure, coronary bypass surgery, angioplasty or with missing data on covariates of interest, implausible energy intake or incomplete dietary information | Exposure: Poultry: details NR but presumably unprocessed; Comparator: Continuous (1 svg/d substitution); - Legumes: details NR; - Nuts: details NR; Assessment methods and timing:; - FFQ at baseline and ~6y follow-up (cumulative average); Outcome assessment methods and timing:; - CHD (definite or probable MI, or CHD death) adjudicated using information from study visits, yearly telephone follow-up calls, review of hospital discharge lists and medical charts, death certificates, next-of-kin interviews, and physician-completed questionnaires; - 22y | [underlined: CHD] by 1 svg/d substitution, HR (95% CI); Legumes for poultry: 1.04 (0.76, 1.44); Nuts for poultry: 1.00 (0.79, 1.27) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (all the food items in the table, fiber intake), total energy intake; - Other: study center, systolic blood pressure, use of antihypertensive and/or lipid lowering medication, HDL, total cholesterol, carbohydrate intake, magnesium intake; Limitations:; - No preregistered data analysis plan; Funding: NHLBI/NIH; German Research Foundation; University of Wurzburg
Lim, 2022^64^; PCS, Singapore, Singapore Multi-Ethnic Cohort; Analytic N = 12408; Participant characteristics:; - Age: 45.6 (13.1)y; 21-65y; - Female: 57%; - Race and/or ethnicity: 45% Chinese, 27% Malay, 28% Indian; - SEP: 30% primary or below, 35% secondary education, 35% tertiary education; - BMI: 24.9 (5.0) kg/m^2^; - Health Status: 9% diabetes; 36% family history of heart disease; Excluded those with heart disease, stroke, or cancer; missing data; ethnicity other than Chinese, Malay, or Indian; reported energy intakes outside of ±3 SDs of the sex-specific mean energy intake | Exposure: Poultry: details NR; 1 svg = 90g; - Also examined red meat: pork, beef, mutton; 1 svg = 90g; Comparator: Continuous (1 svg/d substitution); - Refined grains: such as rice and noodle dishes, other details NR; 1 svg = 100g; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Incidence of major adverse cardiovascular events (MACEs), which included non-fatal acute myocardial infarction, non-fatal stroke, and CVD mortality from medical records through linkage with national registries; - 10.1 (2.3)y | [underlined: Incidence of MACEs] by 1 svg/d substitution, HR (95% CI); Poultry for refined grains: 0.93 (0.73, 1.19); Red meat for refined grains: 0.87 (0.68, 1.11) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (whole grains, fruit, vegetables, seafood, dairy, egg, soy), total energy intake; - Other: history of diabetes or heart disease; HTN; dyslipidemia; menopausal status; Limitations:; - Exposure measured at p>baseline only; - Inadequate adjustment for missing data; - No preregistered data analysis plan; Funding: National Medical Research Council; Biomedical Research Council; Ministry of Health (Singapore); National University of Singapore; National University Health System, Singapore
Sun, 2021^80^; PCS, United States, Women’s Health Initiative; Analytic N = 102,521; Participant characteristics:; - Age: 62 (7)y; 50-79y; - Female: 100%; - Race and/or ethnicity: 82% White; 9% Black; ~4% Hispanic; ~5% Other/Missing; - SEP: 32% high school or less, 27% some college, 40% college or higher; 37% annual income >$50K; - BMI: ~27 (5) kg/m^2^; - Health Status: 48% family history of heart attack; 36% family history of stroke; Excluded those with missing data, energy intake <600 or >5000 kcal/d, CVD or cancer at baseline | Exposure: Poultry: chicken, turkey, and other poultry; computed into ounce equivalent according to protein content (1 oz meat = 1 oz equivalent of protein food); Comparator: Continuous (2 oz-eq/d substitution); - Nuts: nuts and seeds; computed into ounce equivalent according to protein content (0.5 oz nuts = 1 oz equivalent of protein food); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD mortality (included deaths from atherosclerotic cardiac, definite coronary heart disease, possible coronary heart disease, cerebrovascular disease, pulmonary embolism, and other or unknown cardiovascular disease) from death certificates, medical records, autopsy reports, or linkage to National Death Index; - 18.1y | [underlined: CVD mortality] by 2 oz-eq/d substitution, HR (95% CI); Nuts for poultry: data NR (figure only), P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education, income), physical activity, anthropometry, smoking, alcohol, diet quality (intake of fruit, vegetables, whole grains, SSB, and other protein sources), total energy intake; - Other: hormone use; family history of heart attack/stroke; Limitations:; - Exposure measured at baseline only; - Data not provided beyond figure; - No preregistered data analysis plan; Funding: NHLBI
Würtz, 2016a^85^; PCS, Denmark, Danish Diet, Cancer and Health Analytic N = 55,171; Participant characteristics:; - Age: 56y; 50-64y; - Female: 53%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: ~26 (21-33) kg/m^2^; - Health Status: 16% HTN, 7% hypercholesterolemia; Excluded those with previous diagnosis of cancer or MI, missing data | Exposure: Poultry: chicken and turkey; Comparator: Continuous (150 g/wk substitution); - Vegetables: including fruiting vegetables (cucumber, aubergine, green pepper, red pepper, tomato, zucchini, avocado, green beans, green peas, maize), leafy vegetables (spinach, lettuce), root vegetables (carrot, celeriac, ginger), cabbage (cauliflower, broccoli, red cabbage, white cabbage, kale, Brussels sprouts), mushrooms (champignon, chanterelle), onion (onion, garlic) and stalk vegetables/sprouts (leek, bean sprouts, chives, asparagus, bamboo shoots, rhubarb); also included a few mixed dishes such as salad and vegetable patties, and vegetable content from standard recipes such as stew contributed small amounts Potatoes: including boiled, baked, roasted, fried and mashed potatoes (not including potato chips); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Myocardial infarction (non-fatal and fatal) from national registries, medical records; - 13.5y | [underlined: MI] by 150 g/wk substitution, HR (95% CI); Women; Total vegetables for poultry: 0.99 (0.90, 1.10); Potatoes for poultry: 0.98 (0.89, 1.09); Men; Total vegetables for poultry: 0.96 (0.90, 1.01); Potatoes for poultry: 0.96 (0.91, 1.01); Results also provided by 250 kcal/wk substitutions | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit, sweets, lean dairy products, fatty dairy products, potato chips, refined cereals, whole grain cereals, nuts), total energy intake; - Other: menopausal status and use of hormone replacement therapy (women); Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only; - No preregistered data analysis plan; Funding: Danish Council for Strategic Research; Aarhus University; Danish Cancer Society
Zhong, 2021^87^; PCS, United States, Multiple cohorts (ARIC, CARDIA, CHS, FHS, FOS, MESA); Analytic N = 29,682; Participant characteristics:; - Age: 53.7 (15.7)y; - Female: 56%; - Race and/or ethnicity: 69% non-Hispanic White; 24% non-Hispanic Black; 4.5% Hispanic; 2% Chinese; <1% Other; - SEP: 53% some college or more; 47% high school or less; - BMI: NR; - Health Status: Generally healthy; Excluded those with CVD at baseline, missing data, or <500 or >6000 kcal/d | Exposure: Poultry: details NR; 1 svg equivalent to 85.05 g (i.e., 3 oz); Comparator: Continuous (1 svg/wk substitution); - Nuts: including seeds and nut butter; 1 svg equivalent to 28.35 grams (i.e., 1 oz) of nuts or seeds, one tablespoon of nut butter; - Legumes: details NR; 1 svg equivalent to 1/2 cup legumes; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and non-fatal CHD, fatal and non-fatal stroke, fatal and non-fatal heart failure, and other CVD deaths) from medical records and/or autopsy data; - 19y | [underlined: Incident CVD] by 1 svg/wk substitution, HR (95% CI); Nuts for poultry: 0.98 (0.97, 0.99), P<0.01; Legumes for poultry: 0.98 (0.97, 1.00); Results also provided for 1 svg/d substitution, as well as absolute risk difference. | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, smoking, alcohol, diet quality (AHEI), total energy intake; - Other: cohort; other foods (eggs, processed meat, unprocessed red meat, poultry, fish, nuts, legumes, whole grains); hormone therapy; Limitations:; - Did not account for key confounders: Anthropometry; - Exposure measured at baseline only; - Inadequate information on amount of missingness; - No preregistered data analysis plan; Funding: AHA Strategically Focused Research Network; NHLBI; Northwestern University Feinberg School of Medicine

a Abbreviations: AHEI: Alternative Healthy Eating Index; BMI: body mass index; CABG: coronary artery bypass grafting; CHD: coronary heart disease; CHO: carbohydrate; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DBP: diastolic blood pressure; dL: deciliter(s); DM: diabetes mellitus; eq: equivalent; FFQ: food frequency questionnaire; HDL: high-density lipoprotein cholesterol; HTN: hypertension; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); m: meter(s); L: liter(s); LDL: low-density lipoprotein cholesterol; MI: myocardial infarction; mmHg: millimetre of mercury; mmol: millimole(s); mo: month(s); MUFA: monounsaturated fatty acids; NCC: nested case control; NR: not reported; NS: not significant; OR: odds ratio; oz: ounce(s); P: p-value; PCS: prospective cohort study; PUFA: polyunsaturated fatty acids; RCT: randomized controlled trial; RR: risk ratio; SBP: systolic blood pressure; SD: standard deviation; SEM: standard error of the mean; SFA: saturated fatty acids; SEP: socioeconomic position; SSB: sugar-sweetened beverages; svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; TG: triglycerides; wk: week(s); y: year(s)

Table 66 Risk of bias for randomized controlled trial examining white meat compared to plant-based foods in adults and older adults and risk of cardiovascular disease^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bergeron, 2019^58^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 67 Risk of bias for observational studies examining white meat compared to plant-based foods in adults and older adults and risk of cardiovascular disease^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bernstein, 2010^34^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bernstein, 2012^54^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Haring, 2014^38^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Lim, 2022^64^ | LOW* | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Sun, 2021^80^ | LOW* | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Würtz, 2016a^85^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Zhong, 2021^87^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 68 Evidence examining the relationship between white meat compared to fish and seafood in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention/Exposure and Comparator | Results | Methodological Considerations
Bernstein, 2010^34^; PCS, United States, NHS; Analytic N = 84,136; Participant characteristics:; - Age: ~58y; 30-55y; - Female: 100%; - Race and/or ethnicity: Mostly White; - SEP: All nurses/health professionals; - BMI: ~26 kg/m^2^; - Health Status: 34% history of high BP; 36%history of high cholesterol; Excluded participants with incomplete FFQ; implausible TEI; previously diagnosed cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of coronary artery bypass grafting) | Exposure: Poultry: chicken with and without skin, chicken sandwich, and chicken/turkey hot dog; Comparator: Continuous (1 svg/d substitution); - Fish: canned tuna, dark- and light-fleshed fish, and breaded fish; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - CHD (nonfatal MI and fatal CHD) from medical records, state vital records, National Death Index, postal system or report by kin; - 26y | [underlined: CHD] by 1 svg/d substitution, RR (95% CI); Fish for poultry: Data NR (figure only), P=NS | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, trans fat), total energy intake; - Other: time period, menopausal status, parental history of early myocardial infarction, years of multivitamin use, vitamin E supplement use, aspirin use; Limitations:; - Did not account for key confounders: Socioeconomic position; - No preregistered data analysis plan; Funding:; NIH; Unilever
Bernstein, 2012^54^; PCS, United States, NHS, HPFS; Analytic N = 127,160; Participant characteristics:; - Age: NHS ~57y, 30-55y; HPFS ~62y, 40-75y; - Female: 66%; - Race and/or ethnicity: Mostly White; - SEP: All nurses/health professionals; - BMI: ~26 kg/m^2^; - Health Status: ~33% high BP (HPFS & NHS); ~38% high cholesterol (HPFS), 35% high cholesterol (NHS); Excluded participants diagnosed with cancer, diabetes, angina, myocardial infarction, stroke, or other cardiovascular disease (including a history of percutaneous coronary intervention or coronary artery bypass grafting) at baseline; excessive missing data on FFQ; implausible energy intake | Exposure: Poultry: chicken with and without skin, chicken sandwich, and chicken/turkey hot dog; Continuous (1 svg/d substitution); - Fish: canned tuna, dark and light fleshed fish, and breaded fish; Assessment methods and timing:; - FFQ at baseline and every 4y (cumulative average); Outcome assessment methods and timing:; - Stroke [ischemic (thrombotic, embolic, or unspecified non-hemorrhagic), hemorrhagic, or of unknown type] from medical records, autopsy report, death certificate, or report by next-of-kin; - 22-26y | [underlined: Stroke] by 1 svg/d substitution, HR (95% CI); Poultry for fish: 0.89 (0.68, 1.16) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (cereal fiber, fruit and vegetables, trans fat, other protein sources), total energy intake; - Other: time period, parental history of MI (<60y), menopausal status (women), multivitamin use, vitamin E supplement use, aspirin use; Limitations:; - Did not account for key confounders: Socioeconomic position; - Unclear how many participants were excluded for exposure missingness vs. previous diagnosis of a condition; - No preregistered data analysis plan; Funding:; NIH; Harvard Human Nutrition Program
Borgi, 2015^59^; PCS, United States, NHS, NHS II, HPFS; Analytic N = 188,518; (62,273 from NHS I; 88,831 from NHS II; 37,414 from HPFS); Participant characteristics:; - Age: ~36-55y (mean across cohorts and meat, poultry, seafood intake); 25-75y at enrollment; - Female: 80%; - Race and/or ethnicity: ~94% White; mostly non-Hispanic; - SEP: All nurses/health professionals; - BMI: ~23-25 kg/m^2^; - Health Status: All without HTN at baseline; Excluded those with diagnosis of hypertension at baseline; those who did not provide dietary information | Exposure: Poultry (chicken and turkey, with or without skin); Comparator: Continuous (1 svg/d substitution); - Seafood (dark meat fish, other fish, shrimp, lobster, and canned tuna); Assessment methods and timing:; - FFQ at baseline and every 4y; Outcome assessment methods and timing:; - HTN self-reported on annual questionnaires; - 20-26y | [underlined: Incident HTN] by 1 svg substitution, HR (95% CI); Seafood for poultry; NHS: Data NR (figure only), P=NS; NHS II: Data NR (figure only), P=NS; HPFS: 1.09 (1.00, 1.20) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, physical activity, anthropometry, smoking, alcohol, diet quality (fruits and vegetables, whole grains, SSB, artificially sweetened beverages), total energy intake; - Other: family history of HTN; post-menopausal status; oral contraceptive use (in NHS II); use of non-narcotic analgesic use; change in weight; Limitations:; - Did not account for key confounders: Socioeconomic position; - Outcome was self-reported; - No preregistered data analysis plan; Funding:; AHA
Haring, 2014^38^; PCS, United States, ARIC; Analytic N = 12,066; Participant characteristics:; - Age: ~53.8 (5.7)y; 45-64y; - Female: 56%; - Race and/or ethnicity: 77% White; 23% Black; - SEP: 79% high school graduates; - BMI: 27.1 kg/m^2^; - Health Status: 29% HTN; ~26% current smoker; Excluded participants with self-reported diabetes, fasting blood glucose ≥126 mg/dL, non-fasting blood glucose ≥200 mg/dL or use of diabetes medication, a history of myocardial infarction, stroke, heart failure, coronary bypass surgery, angioplasty or with missing data on covariates of interest, implausible energy intake or incomplete dietary information | Exposure: Poultry: details NR but presumably unprocessed; Comparator: Continuous (1 svg/d substitution); - Fish/seafood: details NR; Assessment methods and timing:; - FFQ at baseline and ~6y follow-up (cumulative average); Outcome assessment methods and timing:; - CHD (definite or probable MI, or CHD death) adjudicated using information from study visits, yearly telephone follow-up calls, review of hospital discharge lists and medical charts, death certificates, next-of-kin interviews, and physician-completed questionnaires; - 22y | [underlined: CHD] by 1 svg/d substitution, HR (95% CI) Fish/seafood for poultry: 1.05 (0.76, 1.45) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (all the food items in the table, fiber intake), total energy intake; - Other: study center, systolic blood pressure, use of antihypertensive and/or lipid lowering medication, HDL, total cholesterol, carbohydrate intake, magnesium intake; Limitations:; - No preregistered data analysis plan; Funding:; NHLBI/NIH; German Research Foundation; University of Wurzburg
Venø, 2018^82^; PCS, Denmark, Danish Diet, Cancer and Health; Analytic N = 55,338; Participant characteristics:; - Age: 56.1y; 50-64y; - Female: 52%; - Race and/or ethnicity: NR; - SEP: 21% with >10y schooling, 46% with 8-10y, 33% with <7y; - BMI: 25.5 kg/m^2^; - Health Status: 16% HTN, 7% hypercholesterolemia; Excluded those with missing data; cancer or stroke | Exposure: Poultry: details NR; Comparator: Continuous (150 g/wk substitution); - Total fish: lean and fatty fish combined; - Lean fish: defined by a low content of n-3 PUFA (≤1 g/100 g); - Fatty fish: defined by a high content of n-3 PUFA (>1 g/100 g); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Ischemic stroke (subtypes included large artery atherosclerosis, cardioembolism, small-vessel occlusion, stroke of other etiology, and stroke of undetermined etiology) from Danish National Patient Register; - 13.5y | [underlined: Total ischemic stroke] by 150 g/wk substitution, HR (95% CI); Total fish for poultry: 1.00 (0.93, 1.07); Lean fish for poultry: 1.01 (0.93, 1.11); Fatty fish for poultry: 0.98 (0.89, 1.08); Results also provided for ischemic stroke subtypes | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, total energy intake; - Other: hypercholesterolemia, diabetes mellitus, HTN, atrial fibrillation/atrial flutter; Limitations:; - Did not account for key confounders: Race and/or ethnicity, diet quality; - Did not clearly define all dietary exposures analyzed; - Exposure measured at baseline only; - No preregistered data analysis plan; Funding:; Danish Heart Foundation; Danish Cancer Society
Würtz, 2016b^86^; PCS, Denmark, Danish Diet, Cancer and Health; Analytic N = 55,171 (29,142 women; 26,029 men); Participant characteristics:; - Age: ~56y; 50-64y; - Female: 53%; - Race and/or ethnicity: NR, 100% born in Denmark; - SEP: 32% <8y education; - BMI: ~26 (21-33) kg/m^2^; - Health Status: 2% T2D; 16% HTN; 7% hypercholesterolemia; Excluded those with cancer or MI at baseline, missing baseline data | Exposure: Poultry: chicken and turkey; Comparator: Continuous (150 g/wk substitution); - Total fish: unprocessed and processed fish and shellfish; - Lean fish: ≤1g omega-3 PUFA per 100g (lean white fish, canned tuna and sardines, shellfish, cod roe); - Fatty fish: >1g omega-3 PUFA per 100g (darker fish such as salmon, trout, herring, fresh and canned mackerel, lumpfish roe); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Myocardial infarction (fatal and nonfatal) from Danish National Patient Register and in the Danish Cause of Death Register; - 13.5y | [underlined: MI] per 150 g/wk substitution, HR (95% CI); Fish for poultry; All: 0.96 (0.90, 1.02); Women: 0.95 (0.83, 1.09); Men: 0.96 (0.90, 1.03); Lean fish for poultry; All: 1.00 (0.93, 1.08); Women: 1.06 (0.90, 1.24); Men: 0.99 (0.91, 1.07); Fatty fish for poultry; All: 0.91 (0.83, 0.99); Women: 0.82 (0.68, 0.99); Men: 0.94 (0.85, 1.03) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit, vegetables, sweets, soft drinks, lean and fatty dairy products, fatty potatoes, refined and whole grain cereals, nuts), total energy intake; - Other: menopausal status; HRT use; HTN; Hypercholesterolemia; T2D; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Diet measured at baseline only; - No preregistered data analysis plan; Funding:; Danish Council for Strategic Research; Aarhus University; Danish Cancer Society
Zhong, 2021^87^; PCS, United States, Multiple cohorts (ARIC, CARDIA, CHS, FHS, FOS, MESA); Analytic N = 29,682; Participant characteristics:; - Age: 53.7 (15.7)y; - Female: 56%; - Race and/or ethnicity: 69% non-Hispanic White; 24% non-Hispanic Black; 4.5% Hispanic; 2% Chinese; <1% Other; - SEP: 53% some college or more; 47% high school or less; - BMI: NR; - Health Status: Generally healthy; Excluded those with CVD at baseline, missing data, or <500 or >6000 kcal/d | Exposure: Poultry: details NR but presumably unprocessed; 1 svg equivalent to 85.05 g (i.e., 3 oz); Comparator: Continuous (1 svg/wk substitution); - Fish: details NR; 1 svg equivalent to 85.05 g (i.e., 3 oz); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and non-fatal CHD, fatal and non-fatal stroke, fatal and non-fatal heart failure, and other CVD deaths) from medical records and/or autopsy data; - 19y | [underlined: Incident CVD] by 1 svg/wk substitution, HR (95% CI); Fish for poultry: 0.99 (0.97, 1.00); Results also provided for 1 svg/d substitution, as well as absolute risk difference. | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, smoking, alcohol, diet quality (AHEI), total energy intake; - Other: cohort; other foods (eggs, processed meat, unprocessed red meat, poultry, fish, nuts, legumes, whole grains); hormone therapy; Limitations:; - Did not account for key confounders: Anthropometry; - Exposure measured at baseline only; - Inadequate information on amount of missingness; - No preregistered data analysis plan; Funding:; AHA Strategically Focused Research Network; NHLBI; Northwestern University Feinberg School of Medicine

Table 69 Risk of bias for observational studies examining white meat compared to fish and seafood in adults and older adults and risk of cardiovascular disease^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bernstein, 2010^34^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bernstein, 2012^54^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Borgi, 2015^59^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Haring, 2014^38^ | LOW ^*^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Venø, 2018^82^ | HIGH | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Würtz, 2016a^85^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Zhong, 2021^87^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 70 Evidence examining the effect of meat consumption compared to plant-based foods in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention/Exposure and Comparator | Results | Methodological Considerations
Bergeron, 2019^58^; RCT-crossover, United States, APPROACH (Animal and Plant Protein and Cardiovascular Health); Analytic N = 113; Adequately powered: No; Study aims: To test for differences in lipoprotein effects of diets in which the main source of protein is red meat compared with diets with similar total protein content derived from white meat (poultry) or plant protein sources, and to determine whether these effects were modified by high compared with low SFA intake.; Participant characteristics:; - Age: ~44 (12)y; 21-65y; - Female: 61%; - Race and/or ethnicity: 55% White, 20% Asian, 12% African American, 13% Other; - SEP: NR; - BMI: 26 (3.8) kg/m^2^; 42% with overweight, 16% with obesity; - Health Status: Majority normotensive; Excluded those using tobacco or recreational drugs; lipid-, glucose-, or bloodpressure-lowering medications, blood thinners, or hormones; unwillingness to consume all key study foods; weight loss >3% body weight in 3mo preceding study onset; history of coronary artery disease, diabetes, or other chronic disorder; BMI <20 or >35 kg/m^2^; blood pressure ≥150/90; fasting glucose ≥7 mmol/L, total and LDL cholesterol >95^th^% for sex and age; fasting triacylglycerol ≥5.65 mmol/L; unwillingness to refrain from use of vitamin supplements and alcoholic beverages during study | Intervention: Lean red meat: 11% energy from lean cuts of grain-finished beef and 1% energy from lean cuts of pork; Comparator: Lean white meat: 8% energy from chicken and 4% energy from turkey; Other Comparator: Non-meat sources of protein: legumes, nuts, grains, isoflavonefree soy products; 2-3% of energy from SFA was derived from tropical oils and fats with the remainder from high-fat dairy; Fish, seafood, and processed meats were excluded from all diets. For all diets, the remaining protein (~13% energy) was derived from eggs, dairy, and vegetable sources). Differences in SFA content between the high- and low-SFA arms were achieved primarily by using high-fat dairy products and butter, with only 2-3% energy from SFAs derived from lean red or white meat.; Duration: 4wk each (2-7wk washout) Compliance: Yes, using 24h urinary urea nitrogen and creatinine concentrations to monitor protein intake and weekly collection of menu checklists, grocery receipts, and reported deviations from dietary instructions; Outcome assessment methods and timing:; - LDL, HDL, TG, SBP, DBP; - Fasting blood collection and blood pressure at baseline and 4wk post-baseline | [underlined: LDL (mmol/L)], Mean difference (SE) at 4 wk; Red meat−Non-meat: 0.16 (0.03), P<0.0001; White meat−Non-meat: 0.16 (0.03), P<0.0001; [underlined: HDL (mmol/L)], Mean difference (SE) at 4wk; Red meat−Non-meat: 0.03 (0.01), P=0.007; White meat−Non-meat: 0.04 (0.01), P=0.001; [underlined: TG (mmol/L)], Mean difference (SE) at 4wk; Red meat−Non-meat: −0.03 (0.02), P=0.15; White meat−Non-meat: −0.03 (0.02), P=0.17; [underlined: SBP (mmHg)], Mean (SD) at 4 wk; Non-meat vs. white-meat vs. red meat, between groups: P=0.48; [underlined: DBP (mmHg)], Mean (SD) at 4 wk; Non-meat vs. white-meat vs. red meat, between groups: P=0.87 | Limitations:; - Not sufficiently powered; Funding:; NIH
Daly, 2014^62^; RCT-cluster, Australia; Analytic N = 100; Adequately powered: NR; Study aims: To assess the effects of progressive resistance training combined with a protein-enriched diet facilitated through lean red meat on lean tissue mass, muscle size, strength and function, circulating inflammatory markers, blood pressure, and lipids in elderly women.; Participant characteristics:; - Age: 73y; 60-90y; - Female: 100%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 27 (4) kg/m^2^; - Health Status: 58% on antihypertensive therapy; 38% on lipid-lowering therapy; Excluded those <60y; participation in resistance exercise >1/wk and/or moderate-intensity exercise ≥150 min/wk over past 3 mo; acute or terminal illness; unstable metabolic or cardiovascular disease; history of low-trauma fracture in past 12mo; type 1 diabetes or renal impairment; BMI ≥40 kg/m^2^; use of medication that might have affected muscle metabolism (corticosteroids or thyroxine); substantial weight loss (>0.5 kg) in past 6mo; condition that might have limited participation in trial; inability to commit to the program | Intervention: Lean red meat (N=53): 6 days per week participants consumed two 80g servings of cooked lean red meat per day consumed across 2 meals (~160g cooked meat per day providing ~45g protein); participants could select from a variety of veal, lamb, or beef cuts trimmed of visible fat in labeled 110g portion packs; Comparator: CHO control (N=47): 6 days per week participants consumed ≥1 serving/d (~0.5 cups or ~250 mL or ~75g) cooked rice, pasta, or potato (~25–35 g carbohydrates) with a focus on larger servings of bread, cereals, rice and vegetables and smaller servings of protein foods (e.g., meat and fish). All participants received individual counseling session with a dietitian and sufficient food supplies for their partner when appropriate. All participants were prescribed an individually tailored and supervised progressive resistance and balance-agility training program.; Duration: 4mo; Compliance: Yes, daily consumption recorded on calendar that was collected monthly (81% lean red meat group, 100% CHO group); Outcome assessment methods and timing:; - LDL, HDL, TG, SBP, DBP; - Fasting blood collection at baseline, 2mo, 4mo; blood pressure measured at baseline and 4mo | [underlined: LDL (mmol/L)]; Within group: Mean (SD) at baseline; Mean change (95% CI) at 4mo; CHO: 3.36 (0.96); −0.20 (−0.35, −0.05); Lean red meat: 3.39 (1.01); −0.19 (−0.38, 0.00); Between group: Net difference (95% CI) at 4mo 0.01 (−0.23, 0.25), P-interaction=0.646; [underlined: HDL (mmol/L)]; Within group: Mean (SD) at baseline; Mean change (95% CI) at 4mo; CHO: 1.60 (0.34); −0.02 (−0.07, 0.03); Lean red meat: 1.49 (0.32); −0.01 (−0.05, 0.03); Between group: Net difference (95% CI) at 4mo 0.01 (−0.05, 0.08), P-interaction=0.541; [underlined: TG (mmol/L)]; Within group: Mean (SD) at baseline; Mean change (95% CI) at 4mo; CHO: 1.32 (0.57); 0.01 (−0.10, 0.13); Lean red meat: 1.41 (1.00); −0.11 (−0.30, 0.08); Between group: Net difference (95% CI) at 4mo −0.12 (−0.35, 0.10), P-interaction=0.465; [underlined: SBP (mmHg)]; Within group: Mean (SD) at baseline; Mean change (95% CI) at 4mo; CHO: 134.9 (24.7), −3.5 (−8.5, 1.4); Lean red meat: 137.0 (15.8), −6.6 (−10.9, −2.4); Between group: Net difference (95% CI) at 4mo −3.1 (−9.5, 3.3), P=0.359; [underlined: DBP (mmHg)]; Within group: Mean (SD) at baseline; Mean change (95% CI) at 4mo; CHO: 74.3 (8.4), −0.3 (−3.9, 3.3); Lean red meat: 75.2 (9.3), −3.5 (−5.9, −1.1); Between group: Net difference (95% CI) at 4mo −3.2 (−7.4, 0.9), P=0.219 | Limitations:; - No preregistered data analysis plan; Funding:; Meat and Livestock Australia Ltd; National Health and Medical Research Council; Australian Research Council
Formica, 2020^63^; RCT-parallel, Australia; Analytic N = 154; Adequately powered: NR; Study aims: To investigate whether consumption of lean red meat 3 days/wk could augment the effects of exercise on total body and leg lean mass, thigh muscle cross-sectional area, leg muscle strength, and executive function, in healthy older adults; Participant characteristics:; - Age: 70.7y; 65-84y; - Female: 62%; - Race and/or ethnicity: 84% Caucasian; 16% non-Caucasian; - SEP: 47% university education or higher; 53% high school or lower; - BMI: 27.9 (5) kg/m^2^ (32% with obesity, 35% with overweight); - Health Status: 51% on antihypertensive medication; 34% on lipid-lowering therapy; 15% history of CVD; Excluded those <65y; participation in resistance exercise >1/wk and/or moderate-intensity exercise ≥150 min/wk over past 3 mo; acute or terminal illness; history of low-trauma fracture in past 12mo with functional impairment; chronic liver disease, celiac, or inflammatory bowel disease; BMI >40 kg/m^2^; use of insulin to treat diabetes or oral corticosteroids; condition that might have limited participation in trial; inability to commit to the program | Intervention: Lean red meat (N=77): 3 days/wk on 3 nonconsecutive training days participants consumed two 80g servings of cooked lean red meat per day consumed across 2 meals (~160g cooked meat per day providing ~45g protein); participants were supplied with food every 4wk and could select from a variety of veal, lamb, or beef cuts trimmed of visible fat in labeled 110g portion packs; On nontraining days, participants were advised to maintain their normal diet.; Comparator: CHO control (N=77): 3 days/wk on 3 nonconsecutive training days participants consumed ≥0.5 cup of uncooked rice or pasta, or 1 medium-sized potato (~25–35 g carbohydrates); On the nontraining days, participants were advised to continue to incorporate larger servings of breads, cereals, rice, pasta and vegetables (carbohydrates) and smaller amounts of protein foods (e.g., meat, fish, and chicken) into their usual diet.; Duration: 24wk; Compliance: Yes, daily consumption recorded on calendar that was collected monthly (87% lean red meat group, 91% CHO group); Outcome assessment methods and timing:; - LDL, HDL, TG, SBP, DBP; - Fasting blood collection at baseline, 12wk, 24wk; blood pressure measured at baseline and 24wk | [underlined: LDL (mmol/L)]; Within group: Mean (SD) at baseline; Mean change (95% CI) at 24wk; CHO: 3.05 (0.93); −0.03 (−0.14, 0.09), P=0.620; Lean red meat: 2.82 (1.03); −0.01 (−0.14, 0.13), P=0.992; −0.09 (−0.21, 0.03), P=0.121; Between group: Net difference (95% CI) at 24wk −0.07 (−0.23, 0.10), P-interaction=0.429; [underlined: HDL (mmol/L)]; Within group: Mean (SD) at baseline; Mean change (95% CI) at 24wk; CHO: 1.69 (0.49); 0.01 (−0.04, 0.06), P=0.707; Lean red meat: 1.68 (0.43); 0.05 (0.01, 0.09), P=0.008; 0.02 (−0.02, 0.06), P=0.273; Between group: Net difference (95% CI) at 24wk 0.01 (−0.05, 0.07), P-interaction=0.701; [underlined: TG (mmol/L)]; Within group: Mean (SD) at baseline; Mean change (95% CI) at 24wk; CHO: 1.29 (0.58); −0.03 (−0.11, 0.05), P=0.537; Lean red meat: 1.14 (0.45); −0.01 (−0.09, 0.07), P=0.986; −0.06 (−0.14, 0.02), P=0.145; Between group: Net difference (95% CI) at 24wk −0.03 (−0.14, 0.08), P-interaction=0.558; [underlined: SBP (mmHg)]; Within group: Mean (SD) at baseline; Mean change (95% CI) at 24wk; CHO: 131.5 (15.70); −4.1 (−7.9, −0.4), P=0.052; Lean red meat: 127.5 (14.2); −3.2 (−6.5, 0.0), P=0.027; Between group: Net difference (95% CI) at 24wk 0.9 (−4.0, 5.9), P=0.972; [underlined: DBP (mmHg)]; Within group: Mean (SD) at baseline; Mean change (95% CI) at 24wk; CHO: 73.0 (8.8); −1.7 (−3.7, 0.4), P=0.098; Lean red meat: 72.5 (10.5); −2.7 (−4.9, −0.5), P=0.014; Between group: Net difference (95% CI) at 24wk −1.0 (−4.0, 2.0), P=0.513 | Limitations:; - Interventions were not matched on background diet advice; Funding:; Meat and Livestock Australia Ltd
Maki, 2020^67^; RCT-crossover, United States; Analytic N = 33; Adequately powered: NR; Study aims: To compare the USDA Healthy US-Style Eating Pattern, low in saturated fat and red meat (<40 g/d red meat), with a modified version with an additional 150 g/d lean beef as an isocaloric replacement for carbohydrate on insulin sensitivity and cardiometabolic risk markers.; Participant characteristics:; - Age: 44.4 (2.4)y; 18-74y; - Female: 79%; - Race and/or ethnicity: 73% White/Caucasian; 15% Black/African American; 12% Other; - SEP: NR; - BMI: 31.3 (0.8) kg/m^2^; - Health Status: All with MetS and/or prediabetes; Excluded those with atherosclerotic CVD, pulmonary, endocrine, chronic inflammatory, hepatic, renal, hematologic, immunologic, dermatologic, neurologic, psychiatric, or biliary disorders, or recent cancer other than nonmelanoma skin cancer; significant weight change (±4.5 kg in past 3mo), extreme dietary habits; history of or strong potential for drug or alcohol abuse; uncontrolled HTN (SBP ≥160 mm Hg and/or DBP ≥100 mm Hg); allergy, sensitivity, or intolerance to study foods; unstable use of antihypertensive medication; actively using antibiotics, supplements, or medications known to alter lipid metabolism (except for stable use of statins), carbohydrate metabolism, or weight-loss drugs/programs; pregnant (or planning to be pregnant during study period), lactating, or of childbearing potential and unwilling to commit to use of a medically approved form of contraception throughout study period | Intervention: USDA-LB: additional 150 g/d of lean, unprocessed beef as an isocaloric replacement for carbohydrate, primarily refined starches (providing 25-30% of energy from protein and 40-45% from CHO); Comparator: USDA-CON: <40 g/d lean beef (providing 16-18% of energy from protein and 52-58% from CHO) Both eating patterns were designed to provide ~25–30% of fat energy (6% SFAs, 7% PUFAs, and 12% MUFAs).; Duration: 28d each (≥14d washout) Compliance: Yes, participants had a median compliance of 100% based on consumption of entrees; Outcome assessment methods and timing:; - LDL, HDL, TG, SBP, DBP; - Fasting blood collection and blood pressure measured at baseline and after each 28d diet period | [underlined: LDL (mg/dL)], Mean (±1 SD); Baseline: 112 (85.8, 145); USDA-CON: 105 (85.4, 130); USDA-LB: 109 (88.3, 134); Between group: 28d; P=0.318; [underlined: HDL (mg/dL)], Mean (±1 SD); Baseline: 47.6 (38.7, 58.7); USDA-CON: 44.6 (39.1, 50.9); USDA-LB: 45.5 (39.9, 51.9); Between group: 28d; P=0.447; [underlined: TG (mg/dL)], Mean (±1 SD); Baseline: 115 (72.2, 183); USDA-CON: 111 (75.4, 163); USDA-LB: 113 (76.7, 166); Between group: 28d; P=0.697; [underlined: SBP (mmHg)], Mean (±1 SD); Baseline: 121 (108, 136); USDA-CON: 120 (111, 129); USDA-LB: 120 (112, 130); Between group: 28d; P=0.808; DBP (mmHg), Mean (±1 SD); Baseline: 80.4 (72.0, 89.7); USDA-CON: 79.4 (74.5, 84.5); USDA-LB: 79.4 (74.6, 84.6); Between group: 28d; P=0.914 | Limitations:; - No power calculation for blood lipid outcomes; Funding:; Beef Checkoff
Poddar, 2013^73^; RCT-parallel, United States; Analytic N = 73; Adequately powered: NR; Study aims: Primary: To assess weight loss and weight maintenance efficacy with white button mushrooms as a substitute for red meat over 1 year; Secondary: to assess health parameters on the mushroom vs. meat diet, including blood pressure, lipid profile, and biochemical indicators of inflammation and oxidative stress; Participant characteristics:; - Age: 48.4 (1.4)y; 18-65y; - Female: 88%; - Race and/or ethnicity: 45% White/Caucasian; 53% African American; 2% Hispanic; - SEP: NR; - BMI: all 25-40 kg/m^2^ (inclusion criteria); - Health Status: No uncontrolled chronic health conditions (inclusion criteria); Excluded BMI <25 or >40 kg/m^2^; history of HIV, carcinoma, rheumatoid arthritis, or other uncontrolled chronic health condition; regular use of medications and/or supplements that could affect weight; pregnant or nursing | Intervention: Red meat/Control: ≥90% lean ground beef at 3 meals each week; participants were prescribed a 500 kcal/d energy-deficit diet in first 6mo and received dietary instruction without the recommendation of mushroom substitution; Comparator: Mushroom: substituted white button mushrooms (8oz) for red meat at 3 meals each week by incorporating in sauteed vegetables, “burgers”, and other normally meat-containing dishes; participants were prescribed a 500 kcal/d energy-deficit diet in first 6mo and received dietary instruction on preparing and using mushroom substitutes for meat; Duration: 12mo (6mo weight loss, 6mo weight maintenance); Compliance: No, non-compliance based on <32oz consumption of mushrooms in 2wk; 55% were non-compliant at 0-6mo; 39% non-compliant at 6-12mo; Outcome assessment methods and timing:; - LDL, SBP, DBP; Fasting blood collection and blood pressure at baseline, 3mo, 6mo, and 12mo | [underlined: LDL (mg/dL)], Mean (SEM); Within group: baseline; ∆0-6mo; ∆6-12mo; Mushroom (N=36): 111 (5.50); −1.22 (3.08); −6.68 (5.54); Meat (N=37): 101 (5.56); 1.33 (3.94); −4.97 (4.99); Between group:; ∆0-6mo: P=0.611; ∆6-12mo: P=0.820; [underlined: SBP (mmHg)]; Within group: Mean at baseline; Mean (SEM) at ∆0-6mo; Mushroom (N=14): 132.9; −5.92 (2.98); Meat (N=25): 125.3; 5.52 (5.48); Between group: ∆0-6mo: P=0.150; [underlined: DBP (mmHg)]; Within group: Mean at baseline; Mean (SEM) at ∆0-6mo; Mushroom (N=14): 86.7; −3.71 (2.41); Meat (N=25): 87.2; −1.84 (2.35); Between group: ∆0-6mo: P=0.610 | Limitations:; - Insufficient information on randomization and allocation procedures; - High attrition; - Differences in compliance; - No power calculation; - No preregistered data analysis plan; Funding:; Mushroom Council; Australian Mushroom Growers Association

a Abbreviations: AHEI: Alternative Healthy Eating Index; BMI: body mass index; CABG: coronary artery bypass grafting; CHD: coronary heart disease; CHO: carbohydrate; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DBP: diastolic blood pressure; dL: deciliter(s); DM: diabetes mellitus; eq: equivalent; FFQ: food frequency questionnaire; HDL: high-density lipoprotein cholesterol; HTN: hypertension; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); m: meter(s); L: liter(s); LDL: low-density lipoprotein cholesterol; MI: myocardial infarction; mmHg: millimetre of mercury; mmol: millimole(s); mo: month(s); MUFA: monounsaturated fatty acids; NCC: nested case control; NR: not reported; NS: not significant; OR: odds ratio; oz: ounce(s); P: p-value; PCS: prospective cohort study; PUFA: polyunsaturated fatty acids; RCT: randomized controlled trial; RR: risk ratio; SBP: systolic blood pressure; SD: standard deviation; SEM: standard error of the mean; SFA: saturated fatty acids; SEP: socioeconomic position; SSB: sugar-sweetened beverages; svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; TG: triglycerides; wk: week(s); y: year(s)

Table 71 Risk of bias for randomized controlled trials examining meat compared to plant-based foods in adults and older adults and risk of cardiovascular disease^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bergeron, 2019^58^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Daly, 2014^62^ (cluster) | LOW | NOT APPLICABLE | LOW* | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Formica, 2020^63^ | LOW | NOT APPLICABLE | HIGH* | LOW | LOW | LOW | HIGH
Maki, 2020^67^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Poddar, 2013^73^ | SOME CONCERNS | NOT APPLICABLE | HIGH | SOME CONCERNS | LOW | HIGH | HIGH

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898. ) * Deviations from intended interventions (effect of assignment)

Table 72 Evidence comparing meat with different amounts of saturated fat in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention/Exposure and Comparator | Results | Methodological Considerations
Celada, 2019^61^; RCT-crossover, Spain; Analytic N = 18; Adequately powered: Yes; Study aims: To ascertain the effects of different types of improved fat pâtés and frankfurters in participants at increased CVD risk in terms of a) plasma activated partial thromboplastin time, fibrinogen, and antithrombin; b) serum thromboxane and prostacyclin; c) plasma glucose, insulin, and insulin resistance/sensitivity; and d) plasma LDL, blood pressure, and urine excretion.; Participant characteristics:; - Age: 44.9 (10.3)y; - Female: 0%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 28.6 (2.5) kg/m2 (100% with overweight or obesity); - Health Status: 72% hypercholesterolemia; 22% hypertriglyceridemia; 11% (SBP) and 33% (DBP) hypertension; Included: men with total cholesterol >200 mg/dL; LDL >110 mg/dL, BMI >25 and <34.9 kg/m2; Excluded: use of drugs or phytosterol-enriched beverages/foods to control cholesterol, hypertension, regular consumption of omega-3-enriched food products, intolerance or allergy to meat product components | Intervention: Normal-fat meat products: 200 g/wk normal-fat frankfurter (18% fat) and 250 g/wk normal-fat pâté (30% fat); providing 37g SFA and 1,341 kcal per week; Comparator: Reduced-fat meat products: 200 g/wk reduced-fat frankfurter (15% fat) and 250 g/wk reduced-fat pâté (15% fat); providing 23g SFA and 934 kcal per week Omega-3-enriched meat products: 200 g/wk frankfurter and 250 g/wk pâté in which pork backfat was replaced by combination of olive, flax, and fish oils; provided 13g SFA and 963 kcal per week; Duration: 4wk each (4wk washout); Compliance: Yes, dietary records indicated “adequate introduction” of study foods; Outcome assessment methods and timing:; - LDL, SBP, DBP; - Fasting blood collection and blood pressure collected at start and end of each period | [underlined: LDL (mmol/L)]; Within group: Mean (SD) at baseline, final; rate of change (95% CI); Reduced fat: 3.4 (0.6), 3.5 (0.7); 3.4 (−3.4, 10.1); Normal fat: 3.4 (0.7), 3.7 (0.7); 10 (0.3, 20.7); Between group: rate of change (95% CI); Reduced vs. Normal fat: −6.6 (−15.6, 2.4), P=NS; [underlined: SBP (mmHg)]; Within group: Mean (SD) at baseline, final; rate of change (95% CI); Reduced fat: 120 (10.5), 118 (10); −1.3 (−5.2, 2.5); Normal fat: 125 (13.8), 125 (14.6); 0.7 (−3.2, 4.5); Between group: rate of change (95% CI); Reduced vs. Normal fat: −2 (−7, 3), P=NS; [underlined: DBP (mmHg)]; Within group: Mean (SD) at baseline, final; rate of change (95% CI); Reduced fat: 76.6 (9.6), 76.1 (11.1); −0.1 (−5.8, 5.6); Normal fat: 80 (10.7), 77.5 (13.6); −3 (−9.1, 3); Between group: rate of change (95% CI); Reduced vs. Normal fat: 2.9 (−6.5, 12.3), P=NS; [underlined: LDL (mmol/L)]; Within group: Mean (SD) at baseline, final; rate of change (95% CI); Omega-3: 3.5 (0.7), 3.3 (0.5); −6 (−11.9, 0.01); Normal fat: 3.4 (0.7), 3.7 (0.7); 10 (0.3, 20.7); Between group: rate of change (95% CI); Omega-3 vs. Normal fat: −16 (−26, −5), P<0.05; [underlined: SBP (mmHg)]; Within group: Mean (SD) at baseline, final; rate of change (95% CI); Omega-3: 119 (11), 119 (11), 0.8 (−4.2, 5.8); Normal fat: 125 (13.8), 125 (14.6), 0.7 (−3.2, 4.5); Between group: rate of change (95% CI); Omega-3 vs. Normal fat: 0.1 (−7.8, 8.1), P=NS; [underlined: DBP (mmHg)]; Within group: Mean (SD) at baseline, final; rate of change (95% CI); Omega-3: 77.8 (9.3), 75 (7.9); −3.1 (−7.4, 1.3); Normal fat: 80 (10.7), 77.5 (13.6); −3 (−9.1, 3); Between group: rate of change (95% CI); Omega-3 vs. Normal fat: 0 (−7, 6.9), P=NS | Limitations:; - Order of conditions not randomized; - Potentially underpowered; - No preregistered data analysis plan; Funding:; Spanish National Research Council (CSIC); AGL?
Lytle, 2023^66^; RCT-crossover, United States; Analytic N = 25; Adequately powered: Yes; Study aims: To document the effects of high-fat (HF) ground beef and low-fat (LF) ground beef on voluntary nutrient intake, and to establish if changes in major macronutrient intake were responsible for any changes we observed in lipoprotein cholesterol concentrations; Participant characteristics:; - Age: 40.0 (2.2)y; 25-60y; - Female: 0%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 31.2 (1.8) kg/m^2^; - Health Status: All nonsmokers and not on cholesterol-lowering medications; Excluded those who were women, smokers, on restrictive diets, taking cholesterol-lowering medication, total cholesterol ≤350 mg/dL | Intervention: High-fat ground beef patties (115 g; 24% fat, 10.7 (0.58) g SFA), 5 patties/week, cooking method not specified; Comparator: Low-fat ground beef patties (115 g; 5% fat, 2.44 (0.26) g SFA), 5 patties/week, cooking method not specified; Duration: 5wk each (4wk washout); Compliance: Yes, 78% were compliant; excluded 7 participants for lack of compliance; Outcome assessment methods and timing:; - LDL, HDL, TG; - Fasting blood collection at study entry, after washout, and after each 5wk intervention | [underlined: LDL (mg/dL)], Mean (SEM); Baseline: 131.2 (8.1); After washout: 126.9 (7.9); Within group: 5wk, change from baseline; Low-fat beef: 123.6 (8.5), P<0.05; High-fat beef: 118.5 (7.5), P<0.01; Between group: 5wk; P=NS; [underlined: HDL (mg/dL)], Mean (SEM); Baseline: 49.3 (2.0); After washout: 47.6 (2.2); Within group: 5wk, change from baseline; Low-fat beef: 46.0 (1.9), P<0.001; High-fat beef: 45.4 (1.8), P<0.001; Between group: 5wk; P=NS; [underlined: TG (mg/dL)], Mean (SEM); Baseline: 111.4 (9.6); After washout: 114.6 (10.9); Within group: 5wk, change from baseline; Low-fat beef: 110.1 (8.6), P=NS; High-fat beef: 123.0 (11.1), P<0.05; Between group: 5wk; P=NS | Limitations:; - Did not account for missing data; - Did not prescribe cooking method and unclear whether it differed between groups; Funding:; Beef Checkoff
Würtz, 2016b^86^; PCS, Denmark, Danish Diet, Cancer and Health; Analytic N = 55,171 (29,142 women; 26,029 men); Participant characteristics:; - Age: ~56y; 50-64y; - Female: 53%; - Race and/or ethnicity: NR, 100% born in Denmark; - SEP: 32% <8y education; - BMI: ~26 (21-33) kg/m^2^; - Health Status: 2% T2D; 16% HTN; 7% hypercholesterolemia; Excluded those with cancer or MI at baseline, missing baseline data | Exposure: Lean unprocessed red meat: fresh and minced beef, veal, pork, and lamb (≤10g fat per 100g); Comparator: Continuous (150 g/wk substitution); - Fatty unprocessed red meat: fresh and minced beef, veal, pork, and lamb (>10g fat per 100g); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Myocardial infarction (fatal and nonfatal) from Danish National Patient Register and in the Danish Cause of Death Register; - 13.5y | [underlined: MI] per 150 g/wk substitution, HR (95% CI); Lean unprocessed red meat for fatty unprocessed red meat; All: 0.98 (0.90, 1.07); Women: 1.00 (0.82, 1.22); Men: 0.97 (0.89, 1.07) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit, vegetables, sweets, soft drinks, lean and fatty dairy products, fatty potatoes, refined and whole grain cereals, nuts), total energy intake; - Other: menopausal status; HRT use; HTN; Hypercholesterolemia; T2D; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Diet measured at baseline only; - No preregistered data analysis plan; Funding:; Danish Council for Strategic Research; Aarhus University; Danish Cancer Society

a Abbreviations: AHEI: Alternative Healthy Eating Index; BMI: body mass index; CABG: coronary artery bypass grafting; CHD: coronary heart disease; CHO: carbohydrate; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DBP: diastolic blood pressure; dL: deciliter(s); DM: diabetes mellitus; eq: equivalent; FFQ: food frequency questionnaire; HDL: high-density lipoprotein cholesterol; HTN: hypertension; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); m: meter(s); L: liter(s); LDL: low-density lipoprotein cholesterol; MI: myocardial infarction; mmHg: millimetre of mercury; mmol: millimole(s); mo: month(s); MUFA: monounsaturated fatty acids; NCC: nested case control; NR: not reported; NS: not significant; OR: odds ratio; oz: ounce(s); P: p-value; PCS: prospective cohort study; PUFA: polyunsaturated fatty acids; RCT: randomized controlled trial; RR: risk ratio; SBP: systolic blood pressure; SD: standard deviation; SEM: standard error of the mean; SFA: saturated fatty acids; SEP: socioeconomic position; SSB: sugar-sweetened beverages; svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; TG: triglycerides; wk: week(s); y: year(s)

Table 73 Risk of bias for randomized controlled trials comparing meat with different amounts of saturated fat in adults and older adults and risk of cardiovascular disease^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Celada, 2019^61^ | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Lytle, 2023^66^ | LOW | LOW | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 ) * Deviations from intended interventions (effect of assignment)

Table 74 Risk of bias for observational studies comparing meat with different amounts of saturated fat in adults and older adults and risk of cardiovascular disease^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Würtz, 2016b^88^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 75 Evidence comparing processed meat to unprocessed meat in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention/Exposure and Comparator | Results | Methodological Considerations
RANDOMIZED CONTROLLED TRIALS
Montoro-García, 2022^70^; RCT-crossover, Spain; Analytic N = 54; Adequately powered: Yes; Study aims: To evaluate how a modified dry-cured ham with an improved bioactive peptide composition could ameliorate medium-term BP control together with traditional CV risk factors in individuals with high CV-risk; Participant characteristics:; - Age: 49 (10.3)y; 20-65y; - Female: 35%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 28 (4.8) kg/m^2^; - Health Status: All with stage 1 hypertension, and/or hypercholesterolemia, and/or elevated blood glucose; Excluded those aged <20 or >65y; SBP <130 or >150; DBP <80; BMI <20 or >35 kg/m^2^; TC ≤200 mg/dL and/or glucose ≤100 md/dL | Intervention: Dry-cured ham: 80 g/d, 4.4 (0.3)% SFA, 241.5 (9.3) kcal/100g; Comparator: Cooked ham: 100 g/d, 0.9 (0.01)% SFA, 97.7 (3.9) Kcal/100g; Duration: 4wk each (2wk washout) Compliance: Yes, 100% with acceptable compliance; Outcome assessment methods and timing:; - LDL, HDL, TG, SBP, DBP; - Fasting blood collection at before and after each 8 wk intervention; blood pressure measured by 24h monitoring taken at 20-30min intervals and averaged for 24-h, day and night, before and after each 8 wk intervention | [underlined: LDL (mg/dL)]; Within group: Mean (SD) at baseline, 28d; Dry-cured ham: 130.79 (31.23), 131.35 (32.43), P=NS; Cooked ham: 130.79 (30.41), 130.38 (30.46), P=NS; Between group: Mean difference (95% CI) at 28d; Data NR (figure only), P=NS; [underlined: HDL (mg/dL)]; Within group: Mean (SD) at baseline, 28d; Dry-cured ham: 57.79 (14.14), 55.60 (13.08), P<0.05; Cooked ham: 56.58 (15.08), 56.34 (13.93), P=NS; Between group: Mean difference (95% CI) at 28d; Data NR (figure only), P=NS; [underlined: TG (mg/dL)]; Within group: Mean (SD) at baseline, 28d; Dry-cured ham: 119.83 (60.45), 112.44 (57.31), P=NS; Cooked ham: 136.38 (163.15), 122.15 (61.79), P=NS; Between group: Mean difference (95% CI) at 28d; Data NR (figure only), P=NS; [underlined: SBP (mmHg), Mean 24hr]; Within group: Mean (SD) at baseline, Mean difference (SD) at 28d; Dry-cured ham: 128.38 (11.51), −1.62 (6.89); Cooked ham: 124.05 (9.32), 0.65 (4.66); Between group: Dry-cured – cooked ham effect at 28d −2.41 (−4.39, −0.43); P=0.03820; [underlined: DBP (mmHg), Mean 24hr]; Within group: Mean (SD) at baseline, Mean difference (SD) at 28d; Dry-cured ham: 75.24 (8.25), −1.20 (5.35); Cooked ham: 73.26 (7.93), 1.08 (4.04); Between group: Dry-cured – cooked ham effect at 28d −2.49 (−4.14, −0.84); P=0.02330 | Limitations:; - Methods for randomization and concealment not described; Funding:; MCIN/AEI, ERDF, Fundación Séneca de la Región de Murcia
OBSERVATIONAL STUDIES
Haring, 2014^38^; PCS, United States, ARIC; Analytic N = 12,066; Participant characteristics:; - Age: ~53.8 (5.7)y; 45-64y; - Female: 56%; - Race and/or ethnicity: 77% White; 23% Black; - SEP: 79% high school graduates; - BMI: 27.1 kg/m^2^; - Health Status: 29% HTN; ~26% current smoker; Excluded participants with self-reported diabetes, fasting blood glucose ≥126 mg/dL, non-fasting blood glucose ≥200 mg/dL or use of diabetes medication, a history of myocardial infarction, stroke, heart failure, coronary bypass surgery, angioplasty or with missing data on covariates of interest, implausible energy intake or incomplete dietary information | Exposure: Red meat: unprocessed, details NR; Comparator: Continuous (1 svg/d substitution); - Processed red meat: details NR; Assessment methods and timing:; - FFQ at baseline and ~6y follow-up (cumulative average); Outcome assessment methods and timing:; - CHD (definite or probable MI, or CHD death) adjudicated using information from study visits, yearly telephone follow-up calls, review of hospital discharge lists and medical charts, death certificates, next-of-kin interviews, and physician-completed questionnaires; - 22y | [underlined: CHD] by 1 svg/d substitution, HR (95% CI); Red meat for processed meat: 1.14 (0.90, 1.44) | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (all the food items in the table, fiber intake), total energy intake; - Other: study center, systolic blood pressure, use of antihypertensive and/or lipid lowering medication, HDL, total cholesterol, carbohydrate intake, magnesium intake; Limitations:; - No preregistered data analysis plan; Funding:; NHLBI/NIH; German Research Foundation; University of Wurzburg
Rico-Campa, 2020^75^; PCS, Spain, SUN (Seguimiento; Universidad de Navarra); Analytic N = 13900; Participant characteristics:; - Age: 37.6 (12.3)y; - Female: 67%; - Race and/or ethnicity: NR; - SEP: 100% university graduates; - BMI: 23 (3) kg/m^2^; - Health Status: Generally healthy; Excluded those with follow-up of <2y and 9mo, prevalent hypertension or the habitual use of antihypertensive medication, TEI <500 or >3500 kcal/d for women and <800 or >4000 kcal/d for men, diagnosed with cancer, cardiovascular disease, or diabetes at baseline, no follow-up information, not enough data on cured ham consumption | Exposure: Processed red meat (cured Serrano ham); 1 svg = 50g; Comparator: Continuous (isocaloric substitution); - Boiled ham: details NR but presumably unprocessed red meat; - Processed meat: sausages, hamburgers, and ham; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - HTN self-reported diagnosis, BP of >130/80 mmHg, habitual use of antihypertensive medications; incident hypertension defined as those who did not have hypertension at baseline and reported a new medical diagnosis during f/u; - 10.9y | [underlined: Incident HTN] by iscaloric substitution, HR (95% CI); Boiled ham for cured ham: 0.98 (0.73, 1.33), P=0.92; Processed meat for cured ham: 0.98 (0.69, 1.40),; P=0.93 | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education, marital status), physical activity, anthropometry, smoking, alcohol, diet quality (SSB, ultra-processed foods, adherence to Mediterranean diet, wholefat and low-fat dairy, coffee), total energy intake; - Other: sedentary activity, snacking, following a special diet at baseline, weight changes, sodium intake, potassium intake, family history of hypertension, hypercholesterolemia or depression, SBP and DBP, personality traits (competitive, dependent and relax as continuous); Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only; - Did not account for missing data (those excluded from the analysis); - No preregistered data analysis plan; Funding:; Spanish Government-Instituto de Salud Carlos III, European Regional Development Fund, the Navarra Regional Government, and the University of Navarra
Thao, 2023^81^; PCS, France, E3N; Analytic N = 45,771; Participant characteristics:; - Age: 51.8 (6.3)y; 40-65y; - Female: 100%; - Race and/or ethnicity: NR; - SEP: 36% university education; - BMI: 22.9 (3.2) kg/m^2^; - Health Status: 6% history of CVD; Excluded those with HTN, CVD, stroke, or myocardial infarction; missing dietary data or reporting no meat/fish intake; <1000 or >4000 kcal/d | Exposure: Processed red meat: sausage, ham, charcuterie, and pâté; Comparator: Continuous (150 g/wk substitution); - Unprocessed red meat: beef, pork, rabbit, veal; Assessment methods and timing:; - FFQ at baseline and 12y follow-up (only baseline used in main analysis; followup used in sensitivity analyses); Outcome assessment methods and timing:; - HTN from self-report of date of diagnosis and use of antihypertensive treatments; validated with medication reimbursement; - 18.3y | [underlined: Incident HTN] by 150 g/wk substitution, HR (95% CI) Unprocessed red meat for processed red meat: 0.97 (0.95, 0.99); Data also provided stratified by BMI, smoking status, and history of diabetes; Secondary analysis also conducted using second FFQ | Model adjustments:; - Key confounders: Sex, age (at menopause), socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (SSB intake), total energy intake; - Other: family history of CVD and prevalent diabetes; use of menopausal hormone therapy; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - No preregistered data analysis plan; Funding:; Mutuelle Générale de l’Education Nationale; European Community; French League against Cancer; Gustave Roussy Institute; French Institute of Health and Medical Research; French Research Agency
Würtz, 2016b^86^; PCS, Denmark, Danish Diet, Cancer and Health; Analytic N = 55,171 (29,142 women; 26,029 men); Participant characteristics:; - Age: ~56y; 50-64y; - Female: 53%; - Race and/or ethnicity: NR, 100% born in Denmark; - SEP: 32% <8y education; - BMI: ~26 (21-33) kg/m^2^; - Health Status: 2% T2D; 16% HTN; 7% hypercholesterolemia; Excluded those with cancer or MI at baseline, missing baseline data | Exposure: Unprocessed red meat: fresh and minced beef, veal, pork, and lamb; Comparator: Continuous (150 g/wk substitution); - Processed red meat: red meat items processed via smoking, salting or curing (sausages, salami, smoked or cooked ham, cold cuts, bacon, liver pate); Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - Myocardial infarction (fatal and nonfatal) from Danish National Patient Register and in the Danish Cause of Death Register; - 13.5y | [underlined: MI] per 150 g/wk substitution, HR (95% CI); Unprocessed red meat for processed red meat; All: 0.98 (0.93, 1.02); Women: 1.07 (0.93, 1.22); Men: 0.96 (0.91, 1.01) | Model adjustments:; - Key confounders: Sex, age, socioeconomic position (education), physical activity, anthropometry, smoking, alcohol, diet quality (fruit, vegetables, sweets, soft drinks, lean and fatty dairy products, fatty potatoes, refined and whole grain cereals, nuts), total energy intake; - Other: menopausal status; HRT use; HTN; Hypercholesterolemia; T2D; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Diet measured at baseline only; - No preregistered data analysis plan; Funding:; Danish Council for Strategic Research; Aarhus University; Danish Cancer Society
Zhong, 2021^87^; PCS, United States, Multiple cohorts (ARIC, CARDIA, CHS, FHS, FOS, MESA); Analytic N = 29,682; Participant characteristics:; - Age: 53.7 (15.7)y; - Female: 56%; - Race and/or ethnicity: 69% non-Hispanic White; 24% non-Hispanic Black; 4.5% Hispanic; 2% Chinese; <1% Other; - SEP: 53% some college or more; 47% high school or less; - BMI: NR; - Health Status: Generally healthy; Excluded those with CVD at baseline, missing data, or <500 or >6000 kcal/d | Exposure: Unprocessed red meat: details NR; 1 svg equivalent to 85.05 g (i.e., 3 oz); Comparator: Continuous (1 svg/wk substitution); - Processed meat: 1 svg equivalent to two slices of bacon, two small links of sausage or one hot dog; Assessment methods and timing:; - FFQ at baseline; Outcome assessment methods and timing:; - CVD (fatal and non-fatal CHD, fatal and non-fatal stroke, fatal and non-fatal heart failure, and other CVD deaths) from medical records and/or autopsy data; - 19y | [underlined: Incident CVD] by 1 svg/wk substitution, HR (95% CI); Unprocessed red meat for processed meat: 0.97 (0.95, 1.00), P<0.05; Results also provided for 1 svg/d substitution, as well as absolute risk difference. | Model adjustments:; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position (education), physical activity, smoking, alcohol, diet quality (AHEI), total energy intake; - Other: cohort; other foods (eggs, processed meat, unprocessed red meat, poultry, fish, nuts, legumes, whole grains); hormone therapy; Limitations:; - Did not account for key confounders: Anthropometry; - Exposure measured at baseline only; - Inadequate information on amount of missingness; - No preregistered data analysis plan; Funding:; AHA Strategically Focused Research Network; NHLBI; Northwestern University Feinberg School of Medicine

a Abbreviations: AHEI: Alternative Healthy Eating Index; BMI: body mass index; CABG: coronary artery bypass grafting; CHD: coronary heart disease; CHO: carbohydrate; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DBP: diastolic blood pressure; dL: deciliter(s); DM: diabetes mellitus; eq: equivalent; FFQ: food frequency questionnaire; HDL: high-density lipoprotein cholesterol; HTN: hypertension; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); m: meter(s); L: liter(s); LDL: low-density lipoprotein cholesterol; MI: myocardial infarction; mmHg: millimetre of mercury; mmol: millimole(s); mo: month(s); MUFA: monounsaturated fatty acids; NCC: nested case control; NR: not reported; NS: not significant; OR: odds ratio; oz: ounce(s); P: p-value; PCS: prospective cohort study; PUFA: polyunsaturated fatty acids; RCT: randomized controlled trial; RR: risk ratio; SBP: systolic blood pressure; SD: standard deviation; SEM: standard error of the mean; SFA: saturated fatty acids; SEP: socioeconomic position; SSB: sugar-sweetened beverages; svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; TG: triglycerides; wk: week(s); y: year(s)

Table 76 Risk of bias for randomized controlled trials comparing processed meat to unprocessed meat in adults and older adults and risk of cardiovascular disease^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Montoro-García, 2022^70^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898. ) * Deviations from intended interventions (effect of assignment)

Table 77 Risk of bias for observational studies comparing processed meat to unprocessed meat in adults and older adults and risk of cardiovascular^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Rico-Campa, 2020^75^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Thao, 2023^81^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Würtz, 2016b^86^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Zhong, 2021^87^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi:10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 78 Evidence examining the relationship between plant sources higher in saturated fats compared to vegetable oils higher in unsaturated fat in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Methodological Considerations
Baer, 2021^90^; RCT-crossover, United States; Analytic N = 50; Adequately powered: Yes; Study aims: To determine how consumption of highly-controlled diets containing HOSBO compared to other alternative oils, with similar functional properties, modify LDL-C and other risk factors and biomarkers of CHD. LDL-C was the primary outcome, while secondary outcomes included other measures of lipids and lipoproteins, and markers associated with cardiovascular disease (inflammation, lipid oxidation, blood pressure); Participant characteristics:; - Age: 55.1 (1.4) y; - Female: NR; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 29.5 (0.8) kg/m2; - Health Status: Healthy, moderately elevated LDL-C; Excluded those <30 y or >70 y, with LDL-C <120 or >160 mg/dL, >2 CVD risk factors, disease, taking medications, given birth in last 12 mo, pregnant, lactating, smokers, allergic to study foods, active CVD, and history of weight control surgery, eating disorder, or alcohol or substance abuse | Intervention and comparators:; - Palm oil and palm kernel oil (50:50 PO + PKO): 48% SFA, 37% MUFA, 9% PUFA; - High-oleic soybean oil (HOSBO): 9% SFA, 71% MUFA, 14% PUFA; - 80:20 blend of HOSBO and fully hydrogenated soybean oil (HOSBO+FHSBO): 26% SFA, 57% MUFA, 11% PUFA; - Soybean oil (SBO): 14% SFA, 22% MUFA, 58% PUFA; Intervention duration: 4 wk (12 d washout); Other group differences: Intake of calories, protein, carbohydrate, and fat were similar between groups; Compliance: Yes, all subject fully complied with study protocols; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood lipids and BP measured at day 28 and 29 | [underlined: LDL-C (mg/dL), LS means]; Palm: 133.0; High-oleic soybean oils (HOSBO): 119.8; HOSBO + fully hydrogenated soybean oil (HOSBO+FHSBO): 120.1; Soybean oil (SBO): 115.0; Palm vs HOSBO: p<0.001; Palm vs HOSBO+FHSBO: p<0.001; Palm vs SBO: p=NR; [underlined: HDL-C (mg/dL), LS means]; Palm: 50.4; HOSBO: 48.1; HOSBO + FHSBO: 47.8; Soybean oil (SBO): 47.8; Palm vs HOSBO: p<0.001; Palm vs HOSBO+FHSBO: p<0.001; Palm vs SBO: p=NR; [underlined: TG (mg/dL), LS Means]; Palm: 96.1; HOSBO: 99.7; HOSBO + FHSBO: 101.1; Soybean oil: 92.7; p=0.06; [underlined: SBP (mmHg), LS means]; Palm: 112.4; HOSBO: 111.5; HOSBO +FHSBO: 112.5; SBO: 113.5; p=0.68; [underlined: DBP (mmHg), LS means]; Palm: 67.7; HOSBO: 66.2; HOSBO+FHSBO: 66.5; SBO: 68.0 p=0.17 | Key confounders: NA; Other covariates accounted for: Sex, age, treatment sequence, treatment period, baseline value, interactions of treatment with age and sex; Limitations: No preregistered protocol; Funding: USDA, Qualisoy
Cheng, 2019^91^; RCT-crossover, China; Analytic N = 67; Adequately powered: Yes; Study aims: To investigate the effects of three test oils, i.e., palm olein, cocoa butter and extra virgin olive oil on lipid profiles and LDL-C subfractions; Participant characteristics:; - Age: 23.16 (1.89) y; - Female: 0.51; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 20.9 (1.7) kg/m2; - Health Status: Healthy; Excluded participants who are >40 y or <20 y, BMI > 24 or < 18.5 kg/m2, fasting total cholesterol > 6.2 mmol/L, and fasting triglycerides > 2.3 mmol/L, taking lipidlowering agents, anti-hypertensives, nutritional supplements or oral contraceptives, weight loss programme, history of chronic disease, alcoholism, smokers, pregnant or lactating | Intervention and comparators:; ~11.3%E from:; - Cocoa butter: 64% SFA, 33% MUFA, 3% PUFA; - Palm olein: 35% SFA, 51% MUFA, 15% PUFA; - Olive oil (Extra virgin): 0% SFA, 88% MUFA, 12% PUFA; Intervention duration: 4 wk each (2 wk washout); Other group differences: Dietary intake: No significant differences in total energy, CHO, PRO, Fat, PUFA, Cholesterol.; Significant differences in SFA (all 3 groups), MUFA (all 3 groups). Palm olein: 18.2 g SFA, 24.8 g MUFA, 9.7 g PUFA; Cocoa butter: 24.7 g SFA, 20.8 g MUFA, 7.7 g PUFA; Olive oil: 13.9 g SFA, 31.2 g MUFA, 9.2 g PUFA; Compliance: Yes, high compliance per investigators supervision eating breakfast at school cafeteria daily; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing:; Fasting blood lipids, blood pressure measured at the beginning and the end of 4 wk intervention | [underlined: LDL-C (mmol/L), Mean (SD) at postintervention]; Cocoa butter: 2.97 (0.61); Palm olein: 2.78 (0.63); EVOO: 2.66 (0.63); Cocoa butter vs palm olein: P=NS; Cocoa butter vs EVOO: P≤0.05; Palm olein vs EVOO: P=NS; [underlined: HDL-C (mmol/L), Mean (SD) at postintervention]; Cocoa butter: 1.47 (0.3); Palm olein: 1.51 (0.28); EVOO: 1.46 (0.3); Cocoa butter vs palm olein: P≤0.05; Cocoa butter vs EVOO: P=NS; Palm olein vs EVOO: P=NS; [underlined: TG (mmol/L), Mean (SD) at postintervention]; Cocoa butter: 0.97 (0.4); Palm olein: 0.99 (0.42); EVOO: 0.99 (0.43); Cocoa butter vs palm olein: P=NS; Cocoa butter vs EVOO: P=NS; Palm olein vs EVOO: P=NS; [underlined: SBP (mmHg), Mean (SD)]; Cocoa butter: 108.2 (11.5); Palm olein: 110.4 (12.5) Olive oil: 109.7 (9.7); Palm olein vs. Olive oil: 0.580 (−1.948, 3.108), P=0.650; Cocoa butter vs. Olive oil: −1.068 (−3.596, 1.461), P=0.405; Palm olein vs. Cocoa butter: 1.648 (0.883, 4.178), P=0.213; [underlined: DBP (mmHg), Mean (SD)]; Cocoa butter: 72.7 (8.9); Palm olein: 72.1 (8.5) Olive oil: 73.0 (7.2); Palm olein vs. Olive oil: −1.151 (−2.907, 0.606), P=0.197; Cocoa butter vs. Olive oil: −0.749 (−2.513, 1.015), P=0.402; Palm olein vs. Cocoa butter: −0.402 (2.157, 1.353), P=0.651 | Key confounders: NA; Other covariates accounted for: Baseline indices, age, gender; Limitations: Randomization methods NR.; Funding: Nutrition Fund Chinese Nutrition Society; Fundamental Research Funds for the Central Universities; Research Innovation Program for College Postgraduates; National Key Project of Research and Development Plan
Cox, 1998^8^; RCT-crossover, New Zealand; Analytic N = 37; Adequately powered: NR; Study aims: To determine plasma levels of lathosterol, lipids, lipoproteins and apolipoproteins during diets rich in butter, coconut fat and safflower oil.; Participant characteristics:; - Age: 35 (9)y in men and 39 (9)y in women; 19-72y; - Female: 41%; - Race and/or ethnicity: All Pacific Islanders; - SEP: NR; - BMI 29.7 (3.5) kg/m2 in men, 26.8 (5.4) kg/m2 in women; - Health Status: Healthy; Excluded those with plasma cholesterol <4.2 or >7.5 mmol/L and plasma TG ≥3 mmol/L | Intervention and comparators:; - Coconut oil: participants were instructed to eat coconut cream, coconut bread, monounsaturated margarine, coconut, fish, meat cheese, chicken, fruit and vegetables, rice, noodles, trim milk and other low fat dairy products and not to eat butter, cream, other margarines, chicken skin, deep-fried takeway foods and vegetable oils (providing 39g fat from coconut oil to give an intake of ~17 g lauric acid); - Butter: participants were instructed to eat butter, cream, butter bread, cheese, meat, fish, chicken, fruit and vegetables, rice, noodles, full cream milk and milk products and were instructed not to eat coconut cream or products, margarine and cooking oils (providing 39g fat from butter plus fat from palmitic acid-rich foods to give an intake of ~17g palmitic acid); - Safflower oil: participants were instructed to eat polyunsaturated margarine, safflower oil, safflower bread, cheese, meat, fish, chicken, fruit and vegetables, rice, noodles, trim milk, low fat dairy products and not to eat butter, cream, coconut cream and products, cream, reduced fat cream and deep-fried takeaway foods (providing 24g fat from safflower oil to give an intake of ~17 g linoleic acid); Intervention duration: 6 wk (no washout); Other group differences: Dietary intake: NR; Compliance: Yes, per plasma triglyceride fatty acid composition; Outcome(s): LDL-C, HDL-C, TG; Outcome assessment methods and timing:; Fasting blood collection at baseline and at week 4 and week 6 of each 6wk period (reported results for 4wk values, noting there was no significant change from 4 to 6wk in cholesterol or TG) | [underlined: LDL-C (mmol/L), Mean (SD) at 4wk]; Coconut oil: 3.79 (0.75); Safflower oil: 3.50 (0.84); Butter: 4.08 (0.89); Coconut oil vs Safflower oil: P<0.01; Butter vs Coconut oil: P<0.01; [underlined: HDL-C (mmol/L), Mean (SD) at 4wk]; Coconut oil: 1.21 (0.27); Safflower oil: 1.06 (0.21); Butter: 1.16 (0.24); Coconut oil vs Safflower oil: P<0.01; Butter vs Coconut oil: P=NS; [underlined: TG (mmol/L), Mean (SD) at 4wk]; Coconut oil: 1.61 (0.93); Safflower oil: 1.77 (1.25); Butter: 1.86 (0.89); Coconut oil vs Safflower oil: P=NS; Butter vs Coconut oil: P=NS | Key confounders: NA; Other covariates accounted for: None; Limitations: Inadequate information on randomization; Order of conditions was sequential for all participants, not counterbalanced; Outcomes measured at week 4 of the 6wk intervention; No power calculation; No preregistered data analysis plan; Funding: Health Research Council of New Zealand; Anderson Telford Trust
Lee, 2017^95^; RCT-crossover, United States; Analytic N = 31; Adequately powered: No; Study aims: To investigate the individual and combined effects of dark chocolate, cocoa, and almonds on lipid, lipoprotein, and apolipoprotein concentrations, vascular health, and oxidative stress in individuals with overweight and obesity; Participant characteristics:; - Age: 46.3 (1.8) y; - Female: 0.42; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 29.6 (0.5) kg/m2; - Health Status: 100% with overweight or obesity, majority with elevated total cholesterol (210.0 (6.6) mg/dL) and LDLC (138.3 (5.7) mg/dL); Excluded those with BMI <25 and >40 kg/m2, age <30 y or >70 y, LDL-C <25th or >95th percentile, smokers, elevated blood pressure, history of chronic disease, taking supplements/medications, pregnancy or lactating, following vegetarian diet, nut allergies | Intervention and comparators:; - Chocolate: 9.4 g SFA, 5.1 g MUFA, 0.6 g PUFA 18 g of natural cocoa powder + 43 g of dark chocolate (251.1 kcal) per day;; - Almonds: 42.5 g (253 kcal) of raw almonds per day; 1.7 g SFA, 13.8 g MUFA, 5.5 g PUFA; Intervention duration: 4 wk (2 wk washout); Other group differences: Dietary intake: NR (based on high compliance, background diets were similar between groups); Compliance: Yes, consumed all meals and snacks provided on 95.2% of reported days per daily food logs; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood lipids and BP measured before and after each diet period | [underlined: LDL-C (mg/dl), Mean (SEM), % Change from baseline]; Baseline: 138.3 (5.7); Chocolate: 136.1 (2.8), −0.0 (2.6)%; Almond: 126.4 (2.8), −7.7 (2.6); P at endpoint <0.01; P % change from baseline: P=NS; [underlined: HDL-C (mg/dl), Geometric mean (95% CI)]; Baseline: 41.9 (2.0); Chocolate: 41.4 (39.9, 43.0); Almond: 40.2 (38.7, 41.7); P at endpoint=0.11; P % change from baseline: P=NS; [underlined: TG (mg/dl), Geometric mean (95% CI)]; Baseline: 137.1 (116.7-161); Chocolate: 135.5 (122.3, 150.1); Almond: 128.4 (115.8, 142.3); P at endpoint=0.45; P % change from baseline: P=NS; [underlined: SBP (mmHg), Mean (SEM)]; Baseline: 119.8 (115-124.8); Chocolate: 117.3 (114.8-119.9), −1.2 (1.3)%; Almond: 113.3 (110.9-115.8), −5 (1.3)% p=0.06; [underlined: DBP (mmHg), Mean (SEM)]; Baseline: 82 (1.6); Chocolate: 79.8 (1); Almond: 78.4 (1); p=0.49 | Key confounders: NA; Other covariates accounted for: Treatment, visit, sex, baseline values, age, BMI; Limitations: No preregistered protocol; Funding: The Hershey Company, the Almond Board of California, Pennsylvania State University, NIH
Loganathan, 2022^96^; RCT-crossover, Malaysia Analytic N = 40; Adequately powered: NR; Study aims: To investigate the chronic effects of diets enriched with palm olein, cocoa butter, or extra virgin olive oil with oleic acid primarily at the sn-2 position of the TG molecule on lipid responses in 40 healthy volunteers.; Participant characteristics:; - Age: 33.7 (4.8) y; 20-50 y; - Female: 85%; - Race and/or ethnicity: Malay: 93%, India: 7%; - SEP: NR; - BMI: 21.7 (3.8) kg/m2; - Health Status: Healthy; Excluded participants <20 y or >50 y, BMI <18.5 or ≥25, with hyperlipidemia or hypertension, taking medications/nutraceuticals to reduce blood lipids and pressure, history of chronic diseases, habitual smokers, pregnant or lactating | Intervention and comparators: 16%E from:; - Cocoa butter: 63% SFA, 33% MUFA, 3% PUFA; - Palm olein: 40% SFA, 48% MUFA, 13% PUFA; - Olive oil (extra virgin): 17% SFA, 72% MUFA, 11% PUFA; Intervention duration: 4 wk (2 wk washout); Other group differences: Dietary intake: NR (based on high compliance, background diets were similar between groups); Compliance: Yes, high compliance per high overall meal attendance and visual analog scales; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood lipids measured at baseline and at end of 4 wk dietary periods; blood pressure measured biweekly | [underlined: LDL-C (mmol/L), Mean (SD) at post-intervention]; Cocoa butter: 2.97 (0.61); Palm olein: 2.78 (0.63); EVOO: 2.66 (0.63); Cocoa butter vs EVOO: P=NS; [underlined: Cocoa butter vs EVOO: P≤0.05]; Palm olein vs EVOO: P=NS; [underlined: HDL-C (mmol/L), Mean (SD) at postintervention]; Cocoa butter: 1.47 (0.3); Palm olein: 1.51 (0.28); EVOO: 1.46 (0.3); [underlined: Cocoa butter vs palm olein: P≤0.05]; Cocoa butter vs EVOO: P=NS; Palm olein vs EVOO: P=NS; [underlined: TG (mmol/L), Mean (SD) at postintervention]; Cocoa butter: 0.97 (0.4); Palm olein: 0.99 (0.42); EVOO: 0.99 (0.43); Cocoa butter vs palm olein: P=NS; Cocoa butter vs EVOO: P=NS; Palm olein vs EVOO: P=NS; [underlined: SBP (mmHg), Mean (SD)]; Cocoa butter: 113.08 (10.18); Palm olein: 111.25 (9.18); EVOO: 112.19 (11.82); P=NS for all comparisons; [underlined: DBP (mmHg), Mean (SD)]; Cocoa butter: 73.15 (8.73); Palm olein: 71.28 (7.96); EVOO: 72.41 (10.15); P=NS for all comparisons | Key confounders: NA; Other covariates accounted for: Age, period (time periods), sex, sequence, baseline of the marker; Limitations: Randomization methods details NR; Funding: Malaysian Palm Oil Board
Maki, 2018^98^; RCT-crossover, United States; Analytic N = 23; Adequately powered: Yes; Study aims: To assess the effects of corn oil and coconut oil on lipoprotein lipids, glucose homeostasis, and hs-CRP in adult men and women with LDL-C-cholesterol concentrations above desirable levels; Participant characteristics:; - Age: 45.2 (2.3) y, 18-79 y; - Female: 52%; - Race and/or ethnicity: 64% white, 24% Black or African American, 8% Asian or Pacific Islander, 4% unknown; - SEP: NR; - BMI: 27.7 (0.8) kg/m2; - Health Status: Elevated LDL-C (115≤LDL-C≤ 190 mg/dl); Excluded those <18 y or > 79 y, BMI < 18.5 or > 35 kg/m2, LDL-C < 115 or > 190 mg/dL, TG >375 mg/dL, unwilling to follow study protocols, plans to change smoking habits, history of chronic disease, weight change 4.5 kg over the past 3 mo, extreme dietary habits or eating disorder, pregnant or lactating, taking medications, using foods or dietary supplements that might lipid metabolism | Intervention and comparators:; 54 g/d (4 tablespoons), 488 kcal consumed as part of 4 muffins or rolls:; - Coconut oil: ~25g SFA, ~2g MUFA, ~1g PUFA; - Corn oil: ~4g SFA, ~8g MUFA, ~16g PUFA; Intervention duration: 4 wk (3 wk washout); Other group differences: No difference between groups in calories, CHO, PRO, total fat, fiber, cholesterol, sodium, and calcium, except SFAs and UFAs (both p<0.001). Dietary intake: Coconut oil: 25.1% SFA, 19.4% UFA; Corn oil: 10.7% SFA, 33.7% UFA; Compliance: Yes, 98% compliance; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood lipids and BP measured before and after each diet period | [underlined: LDL-C (mg/dL), % change from baseline]; Baseline: 123 (105, 142) mg/dL; Coconut oil: 4.6 (−2.5, 17.5)% Baseline values; Corn oil: −2.7 (−8.9, 11.5)%; p=0.06; [underlined: HDL-C (mg/dL), % change from baseline]; Baseline: 46.0 (38.5, 55.5) mg/dL; Coconut oil: 6.5 (2.7, 17.8)%, P≤0.05; Corn oil: 5.4 (1.4, 10.3)%, P≤0.05; p=NS; [underlined: TG (mg/dL), % change from baseline]; Baseline: 92.5 (76.5, 136) mg/dL; Coconut oil: 6.0 (−3.0, 13.2)%; Corn oil: −2.1 (−9.7, 20.6)%; p=NS; [underlined: SBP (mmHg), change from baseline]; Baseline: 116 (2.2) mmHg; Coconut oil: 1.4 (1.6)%; Corn oil: 0.3 (1.1)%; p=NS; [underlined: DBP (mmHg), change from baseline]; Baseline: 76.0 (1.1) mmHg; Coconut oil: −0.6 (1.1)%; Corn oil: −0.5 (0.9)%; p=NS | Key confounders: NA; Other covariates accounted for: Baseline values; Limitations: Randomization concealment methods NR; Funding: ACH Food Companies
Rosqvist, 2019^99^; RCT-parallel, Sweden Analytic N = 60; Adequately powered: NR; Study aims: To investigate if overeating SFA- and PUFA-enriched diets lead to differential liver fat accumulation in humans with overweight and obesity; Participant characteristics:; - Age: ~42y; 20-55 y; - Female: 38%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: ~28 kg/m2; - Health Status: 100% with overweight or obesity; Excluded those with BMI <25 or >32 kg/m2, <20 or >55 years, with chronic diseases, abnormal lab tests, taking lipid or blood pressure medications, pregnant or lactating, alcohol abuse, claustrophobia, implanted metals, use of drugs influencing energy metabolism, use of omega-3 supplements or extreme diets, regular heavy exercise, intolerance to gluten, egg, or milk protein | Intervention and comparators: ~40 g/d:; - Palm oil: 53.5% SFA, 37.4% MUFA, 9.2% PUFA; - Sunflower oil: 10.7% SFA, 23.9% MUFA, 65.4% PUFA; Intervention duration: 8 wk; Other group differences: Dietary intake: No differences in energy, carbohydrate, protein, and fat. Significant differences in SFA (higher in palm oil), MUFA (higher in palm oil group), PUFA (lower in palm oil group).; Compliance: Yes, high adherence per changes in plasma and adipose tissue; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing:; Fasting blood lipids at baseline and 8 wk post-baseline | [underlined: LDL-C (mmol/L), Mean absolute change from baseline (SD)]; Palm oil: 0.17 (0.45); Sunflower oil: −0.08 (0.41); Difference between groups (95% CI): 0.11 (0.00002, 0.22), P=0.0499; [underlined: HDL-C (mmol/L), Mean absolute change from baseline (SD)]; Palm oil: 0.09 (0.19); Sunflower oil: 0.10 (0.14); Difference between groups (95% CI): 0.005 (−0.05, 0.04), P=0.81; [underlined: TG (mmol/L), Mean absolute change from baseline (SD)]; Palm oil: −0.01 (0.33); Sunflower oil: −0.02 (0.26); Difference between groups (95% CI): 0.003 (−0.08, 0.07), P=0.94; [underlined: SBP (mmHg), Mean absolute change from baseline (SD)] Palm oil: 0.31 (9.2); Sunflower oil: 0.30 (6.9); Difference between groups (95% CI): 0.69 (−1.19, 2.57), P=0.47; [underlined: DBP (mmHg), Mean absolute change from baseline (SD)]; Palm oil: −1.8 (5.4); Sunflower oil: 0.03 (5.2); Difference between groups (95% CI): −0.19 (−1.39, 1.01), P=0.75 | Key confounders: NA; Other covariates accounted for: Baseline values; Limitations: Does not specify when outcomes were measured (protocol indicates 10 wk).; Funding: Swedish Research Council; Swedish Heart-Lung Foundation; Stockholm County Council; Fondation Leducq; Cardiovascular Program, Karolinska Institutet/Stockholm County Council; Swedish Diabetes Foundation; Swedish Nutrition Foundation; Family Ernfors Foundation; Uppsala-Orebro Regional Research Council; Uppsala County Council; Excellence of Diabetes Research in Sweden
Stonehouse, 2020^100^; RCT-crossover, Australia; Analytic N = 38; Adequately powered: NR; Study aims: To test the hypothesis that dietary fats high in SFA, but containing mostly unsaturated fatty acids in the sn-2 position (PO and cocoa butter [CB]) will behave more like an unsaturated fat source (olive oil [OO]) in terms of their effects on lipid profiles, regardless of their total SFA content; Participant characteristics:; - Age: 29.8 (4.8) y; 20- 40y; - Female: NR; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 23 (2.2) kg/m2; - Health Status: Healthy; Excluded those <20 or >40 y, BMI<18.5 or > 27.5 kg/m2, abnormal liver and kidney function, history of chronic diseases, pancreatic insufficiency or fat malabsorption conditions, smoking 6 months prior, lipid/blood pressure lowering medication, high BP, hyperlipidemia, allergic to study foods, pregnant or lactating, taking supplements affecting study outcomes, active weight-loss, hormone-based contraceptives < 3 months prior | Intervention and comparators: 20%E from:; - Cocoa butter: 65% SFA, 33% MUFA, 3% PUFA; - Palm olein (IV64): 39% SFA, 46% MUFA, 13% PUFA; - Olive oil: 20% SFA, 65% MUFA, 15% PUFA; Intervention duration: 4 wk (2 wk washout); Other group differences: Intake of calories, protein, carbohydrate, and total fat were similar between groups; Compliance: Yes, subjects had ~98% compliance; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing:Fasting blood lipids and BP measured before and after each diet period | [underlined: LDL-C (mmol/L), Baseline, Change from baseline (Estimated marginal mean (95% CI))]; Cocoa butter: 2.78 (2.60, 2.97), 0.00 (−0.12, 0.12); Palm olein: 2.79 (2.59, 2.99), 0.07 (−0.01, 0.14); Olive oil: 2.73 (2.53, 2.93),−0.05 (−0.17, 0.08); P for between group =0.05 (text indicated NS); [underlined: HDL-C (mmol/L), Baseline, Change from baseline (Estimated marginal mean (95% CI))]; Cocoa butter: 1.47 (1.35, 1.59), −0.05 (−0.11, 0.0); Palm olein: 1.46 (1.36, 1.56), −0.01 (−0.04, 0.02); Olive oil: 1.44 (1.33, 1.55), 0.0 (−0.04, 0.04); P for between group =0.31; [underlined: TG (mmol/L), Baseline, Change from baseline (Estimated marginal mean (95% CI))]; Cocoa butter: 0.91 (0.80, 1.03), −0.07 (−0.15, 0.01); Palm olein: 0.82 (0.73, 0.92), 0.03 (−0.03, 0.08); Olive oil: 0.85 (0.75, 0.96), 0.01 (−0.09, 0.10); P for between group=0.07; [underlined: SBP (mmHg), estimated marginal mean (95% CI), baseline, change from baseline]; Cocoa butter: 109 (107, 110), 0.44 (−1.76, 2.65); Palm olein: 111 (109, 114), 1.44 (−1.11, 3.98); Olive oil: 109 (107, 112), −2.30 (−4.43, −0.16), P<0.05; P for between group =0.09; [underlined: DBP (mmHg), estimated marginal mean (95% CI), baseline, change from baseline]; Cocoa butter: 67.6 (65.4, 69.9), 0.33 (−1.73, 2.38); Palm olein: 69.4 (67.3, 71.6), 0.52 (−1.39, 2.43); Olive oil: 67.8 (65.7, 69.9), −1.07 (3.24, 1.11); P for between group=0.56 | Key confounders: NA; Other covariates accounted for: weight changes during the study; Limitations: High loss to follow-up not accounted for; Funding: Malaysian Palm Oil Board
Teng, 2010^103^; RCT-crossover, Malaysia; Analytic N = 41; Adequately powered: Yes; Study aims: To compare the effects of a high oleic vegetable oil with that of a partially hydrogenated, and an unhydrogenated and more saturated, vegetable oil on serum inflammatory markers and blood lipids; Participant characteristics:; - Age: 28.8 (9.1) y; - Female: 80%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 21.9 (3.9) kg/m2; - Health Status: Healthy; Excluded those with BMI≥30 kg/m2, waist hip ratio >0.9 for men and >0.8 for women, total cholesterol >5.2 mmol/L, TGs >2.2 mmol/L, LDL-C >3.3 mmol/L, hypertension (BP>150 mmHg/95 mmHg), chronic diseases, taking medication | Intervention and comparators: 54 g of test fat/day:; - Palm stearin: 62% Palmitic acid, 25% Oleic acid; - High oleic palm olein: 20% Palmitic acid, 54% Oleic acid; Intervention duration: 5 wk (7 d washout); Other group differences: Intake of calories, protein, carbohydrate, and fat were similar between groups (p>0.05). Each test diet contained: Palm stearin diet: 16.4% SFA, 10.7% MUFA, 3.8% PUFA; High oleic palm olein: 10.8% SFA, 15.3% MUFA, 8.6% PUFA; Compliance: Yes, all subjects fully complied with study protocols shown by >90% attendance; Outcome(s): LDL-C, HDL-C, TG; Outcome assessment methods and timing: Fasting blood lipids were measured at baseline and at wk 4 and 5 (means reported) | [underlined: LDL-C (mmol/L), LS Means (SEM)]; Palm stearin oil: 2.95 (0.05); High oleic palm olein: 2.69 (0.05); P<0.05; [underlined: HDL-C (mmol/L), LS Means (SEM)]; Palm stearin oil: 1.55 (0.03); High oleic palm olein: 1.63 (0.03); P<0.05; [underlined: TG (mmol/L), LS Means (SEM)]; Palm stearin oil: 0.88 (0.01); High oleic palm olein: 0.83 (0.01); P<0.05 | Key confounders: NA; Other covariates accounted for:; Baseline values; Limitations: Randomization concealment NR; Funding: Malaysian Palm Oil Board

a Abbreviations: β: beta; %E: percent of energy; BMI: body mass index; BP: blood pressure; CHD: coronary heart disease; CHO: carbohydrates; CI: confidence interval; CVD: cardiovascular disease; d: day; DBP: diastolic blood pressure; dL: deciliter; EVOO: extra virgin olive oil; FHSBO: fully hydrogenated soybean oil; g: gram; HDL-C: high density lipoprotein cholesterol; HOSBO: high-oleic soybean oil; hs-CRP: high-sensitive C-reactive protein; kg: kilogram; L: liter; LDL-C: low density lipoprotein cholesterol; LS: least square; m: meter; mg: milligram; mo: months; mmHg: millimeter of mercury; mmol/l: millimoles per liter; MUFA: monounsaturated fatty acid; NA: not applicable; NIH: National Institutes of Health; NR: not reported; NS: non-significant; PO: Palm oil; PRO: protein; PUFA: polyunsaturated fatty acid; RCT: randomized controlled trial; SBO: soybean oil; SBP: systolic blood pressure; SD: standard deviation; SEP: socioeconomic position; SFA: saturated fatty acid; TG: triglycerides; UFA: unsaturated fatty acid; USDA: United States Department of Agriculture; vs: versus; wk: week; y: year

Table 79 Risk of bias for randomized controlled trials comparing plant sources higher in saturated fat compared to vegetable oils higher in unsaturated fat in adults and older adults and risk of cardiovascular disease^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Baer, 2021^90^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Cheng, 2019^91^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Cox, 1998^8^ | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Lee, 2017^95^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Loganathan, 2022^96^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Maki, 2018^98^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Rosqvist, 2019^99^ | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Stonehouse, 2020^100^ | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Teng, 2010^103^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 80 Evidence examining the relationship between palm olein compared to vegetable oils higher in unsaturated fat in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention, Comparator, and Outcome | Results | Methodological Considerations
Cheng, 2019^91^; RCT-crossover, China; Analytic N = 67; Adequately powered: Yes; Study aims: To investigate the effects of three test oils, i.e., palm olein, cocoa butter and extra virgin olive oil on lipid profiles and LDL-C subfractions; Participant characteristics:; - Age: 23.16 (1.89) y; - Female: 51%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 20.9 (1.7) kg/m2; - Health Status: Healthy; Excluded participants who are >40 y or <20 y, BMI > 24 or < 18.5 kg/m2, fasting total cholesterol > 6.2 mmol/L, and fasting triglycerides > 2.3 mmol/L, taking lipid-lowering agents, anti-hypertensives, nutritional supplements or oral contraceptives, weight loss programme, history of chronic disease, alcoholism, smokers, pregnant or lactating | Intervention and comparators: ~11.3%E from:; - Cocoa butter: 64% SFA, 33% MUFA, 3% PUFA; - Palm olein: 35% SFA, 51% MUFA, 15% PUFA; - Olive oil (Extra virgin): 0% SFA, 88% MUFA, 12% PUFA; Intervention duration: 4 wk each (2 wk washout); Other group differences: Dietary intake: No significant differences in total energy, CHO, PRO, Fat, PUFA, Cholesterol.; Significant differences in SFA (all 3 groups), MUFA (all 3 groups). Palm olein: 18.2 g SFA, 24.8 g MUFA, 9.7 g PUFA; Cocoa butter: 24.7 g SFA, 20.8 g MUFA, 7.7 g PUFA; Olive oil: 13.9 g SFA, 31.2 g MUFA, 9.2 g PUFA; Compliance: Yes, high compliance per investigators supervision eating breakfast at school cafeteria daily; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood lipids, blood pressure measured at the beginning and the end of 4 wk intervention | [underlined: LDL-C (mmol/L), Mean (SD) at post-intervention]; Cocoa butter: 2.97 (0.61); Palm olein: 2.78 (0.63); EVOO: 2.66 (0.63); Cocoa butter vs palm olein: P=NS; Cocoa butter vs EVOO: P≤0.05; Palm olein vs EVOO: P=NS; [underlined: HDL-C (mmol/L), Mean (SD) at post-intervention]; Cocoa butter: 1.47 (0.3); Palm olein: 1.51 (0.28); EVOO: 1.46 (0.3); Cocoa butter vs palm olein: P≤0.05; Cocoa butter vs EVOO: P=NS; Palm olein vs EVOO: P=NS; [underlined: TG (mmol/L), Mean (SD) at post-intervention]; Cocoa butter: 0.97 (0.4); Palm olein: 0.99 (0.42); EVOO: 0.99 (0.43); Cocoa butter vs palm olein: P=NS; Cocoa butter vs EVOO: P=NS; Palm olein vs EVOO: P=NS; [underlined: SBP (mmHg), Mean (SD)]; Cocoa butter: 108.2 (11.5); Palm olein: 110.4 (12.5); Olive oil: 109.7 (9.7); Palm olein vs. Olive oil: 0.580 (−1.948, 3.108), P=0.650; Cocoa butter vs. Olive oil: −1.068 (−3.596, 1.461), P=0.405; Palm olein vs. Cocoa butter: 1.648 (0.883, 4.178), P=0.213; [underlined: DBP (mmHg), Mean (SD)]; Cocoa butter: 72.7 (8.9); Palm olein: 72.1 (8.5); Olive oil: 73.0 (7.2); Palm olein vs. Olive oil: −1.151 (−2.907, 0.606), P=0.197; Cocoa butter vs. Olive oil: −0.749 (−2.513, 1.015), P=0.402; Palm olein vs. Cocoa butter: −0.402 (2.157, 1.353), P=0.651 | Key confounders: NA; Other covariates accounted for: Baseline indices, age, gender; Limitations: Randomization methods NR.; Funding: Nutrition Fund Chinese Nutrition Society; Fundamental Research Funds for the Central Universities; Research Innovation Program for College Postgraduates; National Key Project of Research and Development Plan
Karupaiah, 2016^94^; RCT-crossover, Malaysia; Analytic N = 34; Adequately powered: NR; Study aims: To test the effects of mayonnaise prepared with soybean oil vs palm olein on lipid and lipoprotein profiles; Participant characteristics:; - Age: 23.4 (7.0) y; - Female: 53%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 25.1 (4.7) kg/m2; - Health Status: Healthy; Excluded those with a history of atherosclerotic disease, diabetes or hypertension | Intervention and comparators:; ~15 g/d of mayonnaise on a sandwich; - Palm olein-based mayonnaise: 42% SFA, 45% MUFA, 13% PUFA; - Soybean oil-based mayonnaise: 14% SFA, 25% MUFA, 59% PUFA; Intervention duration: 4 wk (2 wk washout); Other group differences: No difference in intake of calories, protein, carbohydrate, fat, cholesterol and fiber between conditions; SFA, MUFA, and PUFA were significantly different between groups (p<0.001).; Compliance: Yes, 100% Complied with study protocol; Outcome(s): LDL-C, HDL-C, TG; Outcome assessment methods and timing: Fasting blood lipids on day 27 and 28 | [underlined: LDL-C (mmol/L), Mean (SD)]; Baseline: 3.37 (0.52); Soybean oil mayo: 3.05 (0.57); Palm olein mayo: 3.22 (0.57); Difference: −0.17 (0.40); p=0.016; [underlined: HDL-C (mmol/L), Mean (SD)]; Baseline: 1.39 (0.27); Soybean oil mayo: 1.21 (0.27); Palm olein mayo: 1.34 (0.30); Difference: −0.12 (0.15); p<0.001; [underlined: TG (mmol/L), Mean (SD)]; Baseline: 0.94 (0.36); Soybean oil mayo: 1.13 (0.54); Palm olein mayo: 1.08 (0.45); Difference: 0.05 (0.28); p=0.285 | Key confounders: NA; Other covariates accounted for: Baseline values; Limitations: Randomization methods NR; No preregistered protocol; Funding: Kewpie Company, Japan
Loganathan, 2022^96^; RCT-crossover, Malaysia Analytic N = 40; Adequately powered: NR; Study aims: To investigate the chronic effects of diets enriched with palm olein, cocoa butter, or extra virgin olive oil with oleic acid primarily at the sn-2 position of the TG molecule on lipid responses in 40 healthy volunteers.; Participant characteristics:; - Age: 33.7 (4.8) y; 20-50 y; - Female: 85%; - Race and/or ethnicity: Malay: 93%, India: 7%; - SEP: NR; - BMI: 21.7 (3.8) kg/m2; - Health Status: Healthy; Excluded participants <20 y or >50 y, BMI <18.5 or ≥25, with hyperlipidemia or hypertension, taking medications/nutraceuticals to reduce blood lipids and pressure, history of chronic diseases, habitual smokers, pregnant or lactating | Intervention and comparators: 16%E from:; - Cocoa butter: 63% SFA, 33% MUFA, 3% PUFA; - Palm olein: 40% SFA, 48% MUFA, 13% PUFA; - Olive oil (extra virgin): 17% SFA, 72% MUFA, 11% PUFA; Intervention duration: 4 wk (2 wk washout); Other group differences: Dietary intake: NR (based on high compliance, background diets were similar between groups); Compliance: Yes, high compliance per high overall meal attendance and visual analog scales; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood lipids measured at baseline and at end of 4 wk dietary periods; blood pressure measured biweekly | [underlined: LDL-C (mmol/L), Mean (SD) at post-intervention]; Cocoa butter: 2.97 (0.61); Palm olein: 2.78 (0.63); EVOO: 2.66 (0.63); Cocoa butter vs palm olein: P=NS; [underlined: Cocoa butter vs EVOO: P.0.05]; Palm olein vs EVOO: P=NS; [underlined: HDL-C (mmol/L), Mean (SD) at postintervention]; Cocoa butter: 1.47 (0.3); Palm olein: 1.51 (0.28); EVOO: 1.46 (0.3); [underlined: Cocoa butter vs palm olein: P≤0.05]; Cocoa butter vs EVOO: P=NS; Palm olein vs EVOO: P=NS; [underlined: TG (mmol/L), Mean (SD) at postintervention]; Cocoa butter: 0.97 (0.4); Palm olein: 0.99 (0.42); EVOO: 0.99 (0.43); Cocoa butter vs palm olein: P=NS; Cocoa butter vs EVOO: P=NS; Palm olein vs EVOO: P=NS; [underlined: SBP (mmHg), Mean (SD)]; Cocoa butter: 113.08 (10.18); Palm olein: 111.25 (9.18); EVOO: 112.19 (11.82); P=NS for all comparisons; [underlined: DBP (mmHg), Mean (SD)]; Cocoa butter: 73.15 (8.73); Palm olein: 71.28 (7.96); EVOO: 72.41 (10.15); P=NS for all comparisons | Key confounders: NA; Other covariates accounted for: Age, period (time periods), sex, sequence, baseline of the marker; Limitations: Randomization methods details NR; Funding: Malaysian Palm Oil Board
Lucci, 2016^97^; RCT-parallel, Colombia; Analytic N = 145 (EVOO: n=77, HPO: n=68); Adequately powered: No; Study aims: To test the effects of hybrid palm oil and extra-virgin olive oil on human plasma lipids related to cardiovascular disease risk; Participant characteristics:; - Age: 63.5 (7.2) y; - Female: 92%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 28.3 (3.8) kg/m2; - Health Status: Healthy; Excluded those <50 y, not on a stable dose of statins (for those receiving statin therapy), prior cardiovascular disease, any severe chronic illness, drug or alcohol addiction, and allergic to olive or palm oils | Intervention and comparators: 25 ml/d:; - Hybrid Palm oil (HPO): 31% SFA, 56% MUFA, 11% PUFA; - Olive oil (extra virgin): 15% SFA, 77% MUFA, 6% PUFA; Intervention duration: 3 mo; Other group differences: No difference between groups in total energy, protein, total fat, carbohydrate, and alcohol intake; Compliance: Assessed but NR; Outcome(s): LDL-C, HDL-C, TG; Outcome assessment methods and timing: Fasting blood lipids at baseline and after 3 mo intervention period | [underlined: LDL-C (mg/dL), Mean (SD) at baseline and 3 mo]; Palm oil: 124.0 (38.1), 107.2 (36.4); Olive oil: 116.9 (38.1), 95.7 (33.8); p=0.24; [underlined: HDL-C (mg/dL), Mean (SD) at baseline and 3 mo]; Palm oil: 46.3 (14.2), 44.3 (17.9); Olive oil: 43.5 (10.4), 43.2 (16.6); p=0.83; [underlined: TG (mg/dL), Mean (SD) at baseline and 3 mo]; Palm oil: 194.9 (85.7), 210.8 (136.5); Olive oil: 242.0 (155.6), 245.4 (122.9); p=0.37 | Key confounders: NA; Other covariates accounted for: Baseline values; Limitations: Randomization concealment NR; 3 month visit results not adequately powered; No preregistered study protocol; Funding: Hacienda La Cabana (provided oil samples)
Stonehouse, 2020^100^; RCT-crossover, Australia; Analytic N = 38; Adequately powered: NR; Study aims: To test the hypothesis that dietary fats high in SFA, but containing mostly unsaturated fatty acids in the sn-2 position (palm olein and cocoa butter) will behave more like an unsaturated fat source (olive oil [OO]) in terms of their effects on lipid profiles, regardless of their total SFA content; Participant characteristics:; - Age: 29.8 (4.8) y; 20- 40 y; - Female: NR; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 23 (2.2) kg/m2; - Health Status: Healthy; Excluded those <20 or >40 y, BMI<18.5 or > 27.5 kg/m2, abnormal liver and kidney function, history of chronic diseases, pancreatic insufficiency or fat malabsorption conditions, smoking 6 months prior, lipid/blood pressure lowering medication, high BP, hyperlipidemia, allergic to study foods, pregnant or lactating, taking supplements affecting study outcomes, active weight-loss, hormone-based contraceptives < 3 months prior | Intervention and comparators: 20%E from:; - Cocoa butter: 65% SFA, 33% MUFA, 3% PUFA; - Palm olein (IV64): 39% SFA, 46% MUFA, 13% PUFA; - Olive oil: 20% SFA, 65% MUFA, 15% PUFA; Intervention duration: 4 wk (2 wk washout); Other group differences: Intake of calories, protein, carbohydrate, and total fat were similar between groups; Compliance: Yes, subjects had ~98% compliance; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood lipids and BP measured before and after each diet period | [underlined: LDL-C (mmol/L), Baseline, Change from baseline (Estimated marginal mean (95% CI))]; Cocoa butter: 2.78 (2.60, 2.97), 0.00 (−0.12, 0.12); Palm olein: 2.79 (2.59, 2.99), 0.07 (−0.01, 0.14); Olive oil: 2.73 (2.53, 2.93),−0.05 (−0.17, 0.08); P for between group =0.05 (text indicated NS); [underlined: HDL-C (mmol/L), Baseline, Change][underlined: from baseline (Estimated marginal][underlined: mean (95% CI))]; Cocoa butter: 1.47 (1.35, 1.59), −0.05 (−0.11, 0.0); Palm olein: 1.46 (1.36, 1.56), −0.01 (−0.04, 0.02); Olive oil: 1.44 (1.33, 1.55), 0.0 (−0.04, 0.04); P for between group =0.31; [underlined: TG (mmol/L), Baseline, Change from][underlined: baseline (Estimated marginal mean (95% CI))]; Cocoa butter: 0.91 (0.80, 1.03), −0.07 (−0.15, 0.01); Palm olein: 0.82 (0.73, 0.92), 0.03 (−0.03, 0.08); Olive oil: 0.85 (0.75, 0.96), 0.01 (−0.09, 0.10); P for between group=0.07; [underlined: SBP (mmHg), estimated marginal][underlined: mean (95% CI), baseline, change][underlined: from baseline]; Cocoa butter: 109 (107, 110), 0.44 (−1.76, 2.65); Palm olein: 111 (109, 114), 1.44 (−1.11, 3.98); Olive oil: 109 (107, 112), −2.30 (−4.43, −0.16), P<0.05; P for between group =0.09; [underlined: DBP (mmHg), estimated marginal mean (95% CI), baseline, change from baseline]; Cocoa butter: 67.6 (65.4, 69.9), 0.33 (−1.73, 2.38); Palm olein: 69.4 (67.3, 71.6), 0.52 (−1.39, 2.43); Olive oil: 67.8 (65.7, 69.9), −1.07 (3.24, 1.11); P for between group=0.56 | Key confounders: NA; Other covariates accounted for: weight changes during the study; Limitations: High loss to follow-up not accounted for; Funding: Malaysian Palm Oil Board
Sun, 2018^101^; RCT-crossover, China; Analytic N = 100; Adequately powered: No, power calculated based on total cholesterol; Study aims: To contrast the effects of palm oil and olive oil consumption on the human serum lipid profiles in a healthy Chinese population; Participant characteristics:; - Age: ~40 (9) y; 25-55 y; - Female: 53%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: ~22 (2) kg/m2; - Health Status: Healthy; Excluded those with BMI <18.5 or >24.9 kg/m2, TC >6.20 mmol/L, LDL-C >4.12 mmol/L, HDL-C level <1.04 mmol/L, TG >2.26 mmol/L, fasting blood glucose >6.1 mmol/L, a personal or family history of chronic disease, pregnant or lactating | Intervention and comparators: 48 g/d:; - Palm olein: 31.6% SFA, 49.2% MUFA, 14.1% PUFA; - Olive oil: 12.8% SFA, 78.0% MUFA, 4.3% PUFA; Intervention duration: 5 wk (2 wk washout); Other group differences: No difference between groups in energy, PRO, fat, or CHO intake; Compliance: Yes, high compliance; controlled feeding trial; Outcome(s): LDL-C, HDL-C, TG; Outcome assessment methods and timing: Fasting blood lipids and BP measured before and after each diet period (five times in total) | [underlined: LDL-C (mmol/L), Mean (SD),][underlined: baseline, post-intervention]; Palm olein: 2.52, (0.52), 2.48 (0.50); Olive oil: 2.49 (0.42), 2.51 (0.50); P for between group=0.703; [underlined: HDL-C (mmol/L), Mean (SD),][underlined: baseline, post-intervention]; Palm olein: 1.20 (0.16), 1.21 (0.17); Olive oil: 1.28 (0.25), 1.22 (0.20); P for between group=0.963; [underlined: TG (mmol/L), Mean (SD), baseline, post-intervention]; Palm olein: 1.04 (0.43), 0.93 (0.40); Olive oil: 0.90 (0.30), 0.94 (0.39); P for between group=0.836 | Key confounders: NA; Other covariates accounted for: None; Limitations: Randomization concealment methods NR; Did not describe or account for missing data (loss to follow-up); Funding: Malaysian Palm Oil Board, Fundamental Research Funds for the Central Universities

a Abbreviations: %E: percent of energy; BMI: body mass index; BP: blood pressure; CHO: carbohydrates; d: day; dL: deciliter; DBP: diastolic blood pressure; EVOO: extra virgin olive oil; g: gram; HDL-C: high density lipoprotein cholesterol; HPO: hybrid palm oil; kg: kilogram; LDL-C: low density lipoprotein cholesterol; m: meter; mmHg: millimeter of mercury; mmol/l: millimoles per liter; MUFA: monounsaturated fatty acid; NA: not applicable; NR: not reported; NS: non-significant; PRO: protein; PUFA: polyunsaturated fatty acid; RCT: randomized controlled trial; SBP: systolic blood pressure; SD: standard deviation; SEP: socioeconomic position; SFA: saturated fatty acid; TC: total cholesterol; TG: triglycerides; vs: versus; wk: week; y: year

Table 81 Risk of bias for randomized controlled trials on palm olein compared to vegetable oils higher in unsaturated fat in adults and older adults and risk of cardiovascular disease^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Cheng, 2019^91^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Karupaiah, 2016^94^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Loganathan, 2022^96^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Lucci, 2016^97^ | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Stonehouse, 2020^100^ | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Sun, 2018^101^ | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 82 Evidence examining the relationship between plant sources higher in saturated fats compared to a different food source of saturated fat in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention, Comparator, and Outcome | Results | Methodological Considerations
Cheng, 2019^91^; RCT-crossover, China; Analytic N = 67; Adequately powered: Yes; Study aims: To investigate the effects of three test oils, i.e., palm olein, cocoa butter and extra virgin olive oil on lipid profiles and LDL-C subfractions; Participant characteristics:; - Age: 23.16 (1.89) y; - Female: 51%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 20.9 (1.7) kg/m2; - Health Status: Healthy; Excluded participants who are >40 y or <20 y, BMI > 24 or < 18.5 kg/m2, fasting total cholesterol > 6.2 mmol/L, and fasting triglycerides > 2.3 mmol/L, taking lipid-lowering agents, anti-hypertensives, nutritional supplements or oral contraceptives, weight loss programme, history of chronic disease, alcoholism, smokers, pregnant or lactating | Intervention and comparators:; ~11.3%E from:; - Cocoa butter: 64% SFA, 33% MUFA, 3% PUFA; - Palm olein: 35% SFA, 51% MUFA, 15% PUFA; - Olive oil (Extra virgin): 0% SFA, 88% MUFA, 12% PUFA; Intervention duration: 4 wk each (2 wk washout); Other group differences: Dietary intake: No significant differences in total energy, CHO, PRO, Fat, PUFA, Cholesterol.; Significant differences in SFA (all 3 groups), MUFA (all 3 groups). Palm olein: 18.2 g SFA, 24.8 g MUFA, 9.7 g PUFA; Cocoa butter: 24.7 g SFA, 20.8 g MUFA, 7.7 g PUFA; Olive oil: 13.9 g SFA, 31.2 g MUFA, 9.2 g PUFA; Compliance: Yes, high compliance per investigators supervision eating breakfast at school cafeteria daily; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood lipids, blood pressure measured at the beginning and the end of 4 wk intervention | [underlined: LDL-C (mmol/L), Mean (SD) at post-intervention]; Cocoa butter: 2.97 (0.61); Palm olein: 2.78 (0.63); EVOO: 2.66 (0.63); Cocoa butter vs palm olein: P=NS; Cocoa butter vs EVOO: P≤0.05; Palm olein vs EVOO: P=NS; [underlined: HDL-C (mmol/L), Mean (SD) at post-intervention]; Cocoa butter: 1.47 (0.3); Palm olein: 1.51 (0.28); EVOO: 1.46 (0.3); Cocoa butter vs palm olein: P≤0.05; Cocoa butter vs EVOO: P=NS; Palm olein vs EVOO: P=NS; [underlined: TG (mmol/L), Mean (SD) at post-intervention]; Cocoa butter: 0.97 (0.4); Palm olein: 0.99 (0.42); EVOO: 0.99 (0.43); Cocoa butter vs palm olein: P=NS; Cocoa butter vs EVOO: P=NS; Palm olein vs EVOO: P=NS; [underlined: SBP (mmHg), Mean (SD)]; Cocoa butter: 108.2 (11.5); Palm olein: 110.4 (12.5); Olive oil: 109.7 (9.7); Palm olein vs. Olive oil: 0.580 (−1.948, 3.108), P=0.650; Cocoa butter vs. Olive oil: −1.068 (− 3.596, 1.461), P=0.405; Palm olein vs. Cocoa butter: 1.648 (− 0.883, 4.178), P=0.213; [underlined: DBP (mmHg), Mean (SD)]; Cocoa butter: 72.7 (8.9); Palm olein: 72.1 (8.5); Olive oil: 73.0 (7.2); Palm olein vs. Olive oil: −1.151 (−2.907, 0.606), P=0.197; Cocoa butter vs. Olive oil: −0.749 (− 2.513, 1.015), P=0.402; Palm olein vs. Cocoa butter: −0.402 (− 2.157, 1.353), P=0.651 | Key confounders: NA; Other covariates accounted for: Baseline indices, age, gender; Limitations: Randomization methods NR.; Funding: Nutrition Fund Chinese Nutrition Society; Fundamental Research Funds for the Central Universities; Research Innovation Program for College Postgraduates; National Key Project of Research and Development Plan
Cox, 1998^8^; RCT-crossover, New Zealand; Analytic N = 37; Adequately powered: NR; Study aims: To determine plasma levels of lathosterol, lipids, lipoproteins and apolipoproteins during diets rich in butter, coconut fat and safflower oil.; Participant characteristics:; - Age: 35 (9)y in men and 39 (9)y in women; 19–72y; - Female: 41%; - Race and/or ethnicity: All Pacific Islanders; - SEP: NR; - BMI 29.7 (3.5) kg/m2 in men, 26.8 (5.4) kg/m2 in women; - Health Status: Healthy; Excluded those with plasma cholesterol <4.2 or >7.5 mmol/L and plasma TG ≥3 mmol/L | Intervention and comparators:; - Coconut oil: participants were instructed to eat coconut cream, coconut bread, monounsaturated margarine, coconut, fish, meat cheese, chicken, fruit and vegetables, rice, noodles, trim milk and other low fat dairy products and not to eat butter, cream, other margarines, chicken skin, deep-fried takeway foods and vegetable oils (providing 39g fat from coconut oil to give an intake of ~17 g lauric acid); - Butter: participants were instructed to eat butter, cream, butter bread, cheese, meat, fish, chicken, fruit and vegetables, rice, noodles, full cream milk and milk products and were instructed not to eat coconut cream or products, margarine and cooking oils (providing 39g fat from butter plus fat from palmitic acid-rich foods to give an intake of ~17g palmitic acid); - Safflower oil: participants were instructed to eat polyunsaturated margarine, safflower oil, safflower bread, cheese, meat, fish, chicken, fruit and vegetables, rice, noodles, trim milk, low fat dairy products and not to eat butter, cream, coconut cream and products, cream, reduced fat cream and deep-fried takeaway foods (providing 24g fat from safflower oil to give an intake of ~17 g linoleic acid); Intervention duration: 6 wk (no washout); Other group differences: Dietary intake: NR; Compliance: Yes, per plasma triglyceride fatty acid composition; Outcome(s): LDL-C, HDL-C, TG; Outcome assessment methods and timing: Fasting blood collection at baseline and at week 4 and week 6 of each 6wk period (reported results for 4wk values, noting there was no significant change from 4 to 6wk in cholesterol or TG) | [underlined: LDL-C (mmol/L), Mean (SD) at 4wk]; Coconut oil: 3.79 (0.75); Safflower oil: 3.50 (0.84); Butter: 4.08 (0.89); Coconut oil vs Safflower oil: P<0.01; Butter vs Coconut oil: P<0.01; [underlined: HDL-C (mmol/L), Mean (SD) at 4wk]; Coconut oil: 1.21 (0.27); Safflower oil: 1.06 (0.21); Butter: 1.16 (0.24); Coconut oil vs Safflower oil: P<0.01; Butter vs Coconut oil: P=NS; [underlined: TG (mmol/L), Mean (SD) at 4wk]; Coconut oil: 1.61 (0.93); Safflower oil: 1.77 (1.25); Butter: 1.86 (0.89); Coconut oil vs Safflower oil: P=NS; Butter vs Coconut oil: P=NS | Key confounders: NA; Other covariates accounted for: None; Limitations: Inadequate information on randomization; Order of conditions was sequential for all participants, not counterbalanced; Outcomes measured at week 4 of the 6wk intervention; No power calculation; No preregistered data analysis plan; Funding: Health Research Council of New Zealand; Anderson Telford Trust
Loganathan, 2022^96^; RCT-crossover, Malaysia; Analytic N = 40; Adequately powered: NR; Study aims: To investigate the chronic effects of diets enriched with palm olein, cocoa butter, or extra virgin olive oil with oleic acid primarily at the sn-2 position of the TG molecule on lipid responses in 40 healthy volunteers.; Participant characteristics:; - Age: 33.7 (4.8) y; 20–50 y; - Female: 85%; - Race and/or ethnicity: Malay: 93%, India: 7%; - SEP:; - BMI: 21.7 (3.8) kg/m2; - Health Status: Healthy; Excluded participants <20 y or >50 y, BMI <18.5 or ≥25, with hyperlipidemia or hypertension, taking medications/nutraceuticals to reduce blood lipids and pressure, history of chronic diseases, habitual smokers, pregnant or lactating | Intervention and comparators:; 16%E from:; - Cocoa butter: 63% SFA, 33% MUFA, 3% PUFA; - Palm olein: 40% SFA, 48% MUFA, 13% PUFA; - Olive oil (extra virgin): 17% SFA, 72% MUFA, 11% PUFA; Intervention duration: 4 wk (2 wk washout); Other group differences: Dietary intake: NR (based on high compliance, background diets were similar between groups); Compliance: Yes, high compliance per high overall meal attendance and visual analog scales; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood lipids measured at baseline and at end of 4 wk dietary periods; blood pressure measured biweekly | [underlined: LDL-C (mmol/L), Mean (SD) at post-intervention]; Cocoa butter: 2.97 (0.61); Palm olein: 2.78 (0.63); EVOO: 2.66 (0.63); Cocoa butter vs palm olein: P=NS; Cocoa butter vs EVOO: P≤0.05; Palm olein vs EVOO: P=NS; [underlined: HDL-C (mmol/L), Mean (SD) at post-intervention]; Cocoa butter: 1.47 (0.3); Palm olein: 1.51 (0.28); EVOO: 1.46 (0.3); Cocoa butter vs palm olein: P≤0.05; Cocoa butter vs EVOO: P=NS; Palm olein vs EVOO: P=NS; [underlined: TG (mmol/L), Mean (SD) at post-intervention]; Cocoa butter: 0.97 (0.4); Palm olein: 0.99 (0.42); EVOO: 0.99 (0.43); Cocoa butter vs palm olein: P=NS; Cocoa butter vs EVOO: P=NS; Palm olein vs EVOO: P=NS; [underlined: SBP (mmHg), Mean (SD)]; Cocoa butter: 113.08 (10.18); Palm olein: 111.25 (9.18); EVOO: 112.19 (11.82); P=NS for all comparisons; [underlined: DBP (mmHg), Mean (SD)]; Cocoa butter: 73.15 (8.73); Palm olein: 71.28 (7.96); EVOO: 72.41 (10.15); P=NS for all comparisons | Key confounders: NA; Other covariates accounted for: Age, period (time periods), sex, sequence, baseline of the marker; Limitations: Randomization methods details NR; Funding: Malaysian Palm Oil Board
Stonehouse, 2020^100^; RCT-crossover, Australia; Analytic N = 38; Adequately powered: NR; Study aims: To test the hypothesis that dietary fats high in SFA, but containing mostly unsaturated fatty acids in the sn-2 position (PO and cocoa butter [CB]) will behave more like an unsaturated fat source (olive oil [OO]) in terms of their effects on lipid profiles, regardless of their total SFA content; Participant characteristics:; - Age: 29.8 (4.8) y; 20- 40y; - Female: NR; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 23 (2.2) kg/m2; - Health Status: Healthy; Excluded those <20 or >40 y, BMI<18.5 or > 27.5 kg/m2, abnormal liver and kidney function, history of chronic diseases, pancreatic insufficiency or fat malabsorption conditions, smoking 6 months prior, lipid/blood pressure lowering medication, high BP, hyperlipidemia, allergic to study foods, pregnant or lactating, taking supplements affecting study outcomes, active weight-loss, hormone-based contraceptives < 3 months prior | Intervention and comparators:; 20%E from:; - Cocoa butter: 65% SFA, 33% MUFA, 3% PUFA; - Palm olein (IV64): 39% SFA, 46% MUFA, 13% PUFA; - Olive oil: 20% SFA, 65% MUFA, 15% PUFA; Intervention duration: 4 wk (2 wk washout); Other group differences: Intake of calories, protein, carbohydrate, and total fat were similar between groups; Compliance: Yes, subjects had ~98% compliance; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood lipids and BP measured before and after each diet period | [underlined: LDL-C (mmol/L), Baseline, Change from baseline (Estimated marginal mean (95% CI))]; Cocoa butter: 2.78 (2.60, 2.97), 0.00 (−0.12, 0.12); Palm olein: 2.79 (2.59, 2.99), 0.07 (−0.01, 0.14); Olive oil: 2.73 (2.53, 2.93),−0.05 (−0.17, 0.08); P for between group =0.05 (text indicated NS); [underlined: HDL-C (mmol/L), Baseline, Change from baseline (Estimated marginal mean (95% CI))]; Cocoa butter: 1.47 (1.35, 1.59), −0.05 (−0.11, 0.0); Palm olein: 1.46 (1.36, 1.56), −0.01 (−0.04, 0.02); Olive oil: 1.44 (1.33, 1.55), 0.0 (−0.04, 0.04); P for between group =0.31; [underlined: TG (mmol/L), Baseline, Change from baseline (Estimated marginal mean (95% CI))]; Cocoa butter: 0.91 (0.80, 1.03), −0.07 (−0.15, 0.01); Palm olein: 0.82 (0.73, 0.92), 0.03 (−0.03, 0.08); Olive oil: 0.85 (0.75, 0.96), 0.01 (−0.09, 0.10); P for between group=0.07; [underlined: SBP (mmHg), estimated marginal mean (95% CI), baseline, change from baseline]; Cocoa butter: 109 (107, 110), 0.44 (− 1.76, 2.65); Palm olein: 111 (109, 114), 1.44 (−1.11, 3.98); Olive oil: 109 (107, 112), −2.30 (−4.43, − 0.16), P<0.05; P for between group =0.09; [underlined: DBP (mmHg), estimated marginal mean (95% CI), baseline, change from baseline]; Cocoa butter: 67.6 (65.4, 69.9), 0.33 (− 1.73, 2.38); Palm olein: 69.4 (67.3, 71.6), 0.52 (− 1.39, 2.43); Olive oil: 67.8 (65.7, 69.9), −1.07 (− 3.24, 1.11); P for between group=0.56 | Key confounders: NA; Other covariates accounted for: weight changes during the study; Limitations: High loss to follow-up not accounted for; Funding: Malaysian Palm Oil Board
Sundram, 2007^102^; RCT-crossover, Malaysia; Analytic N = 30; Adequately powered: NR; Study aims: To compare the effects of palm olein (POL), partially hydrogenated soybean oil (PHSO), interesterified soybean oil (IE) on blood lipids and the lipoprotein profile in normolipidemic humans, with a secondary focus on blood glucose, insulin and C-peptide.; Participant characteristics:; - Age: 30 (8) y; - Female: ~66%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 22 (4) kg/m2; - Health Status: Healthy; Excluded those with a family history of atherosclerosis or hypertension, use of tobacco or alcohol, following a weight loss program, taking medication | Intervention and comparators:; ~70% of total daily fat:; - Palm olein: ~70% of total daily fat, 44% SFA, 44% MUFA, 12% PUFA; - Interesterified soybean oil (IE):~70% of total daily fat, 59% SFA, 19% MUFA, 22% PUFA; Intervention duration: 4 wk (no washout); Other group differences: Intake of calories, protein, carbohydrate, and fat were similar between groups; Compliance: Yes, complied with study protocol per stable weight and consistent and similar food intake patterns across all groups.; Outcome(s): LDL-C, HDL-C, TG; Outcome assessment methods and timing: Fasting blood lipids were measured at baseline and the end of each intervention period | [underlined: LDL-C (mmol/L), Mean (SD), % change vs palm olein]; Palm olein: 3.08 (0.54); Interesterified soybean oil: 3.20 (0.61), 3.8% (9.7); p=NS; [underlined: HDL-C (mmol/L), Mean (SD), % change vs palm olein]; Palm olein: 1.43 (0.24); Interesterified soybean oil: 1.30 (0.22), −9.1% (6.7); p<0.05; [underlined: TG (mmol/L), Mean (SD)]; Palm olein: 0.91 (0.34); Interesterified soybean oil: 0.86 (0.28); p=NS | Key confounders: NA; Other covariates accounted for: None; Limitations: Randomization methods NR; No preregistered protocol; Funding: Malaysian Palm Oil Board
van Rooijen, 2021^104^; RCT-crossover, Netherlands; Analytic N = 34; Adequately powered: Yes; Study aims: To investigate the effects of palmitic acid and stearic acid on HDL-C-mediated cholesterol efflux capacity and other cardiometabolic risk markers.; Participant characteristics:; - Age: 61.5 (5.7) y; - Female: 41%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 25.4 (2.5) kg/m2; - Health Status: Generally healthy; Excluded participants aged < 45 y or > 70 y, premenopausal, BMI <18 or > 30 kg/m2, fasting serum TC ≥8 mmol/L, TG ≥4.5 mmol/L, HgA1c ≥6.5%, >3kg weight change in last 3 mo, with chronic diseases, excessive alcohol consumption, ≥ 10 h exercise per week, consuming plant sterol- or stanol-enriched products in last 3 mo, heavy smokers, night shift workers | Intervention and comparators:; 16%E from:; - Palmitic acid-rich blend: 90% palm oil and 10% high-oleic sunflower oil (50.2% SFA, 38.8% MUFA, 7.0% PUFA, 43.5% 16:0, 4.6% 18:0); - Stearic acid-rich blend: 92% allanblackia oil and 8% sunflower oil (50.1% SFA, 39.4% MUFA, 6.9% PUFA, 3.2% 16:0, 46.1% 18:0); Intervention duration: 4 wk (4 wk washout); Other group differences: Dietary intake: No significant differences in total energy, CHO, PRO, total SFA, total MUFA, and total PUFA (omega-6 and omega-3) intake; significantly different in palmitic acid (higher in palm oil), stearic acid (lower in palm oil), and fiber (higher in palm oil); Compliance: Yes, high adherence (99.4% palmitic-acid diet, 99.8% on stearic-acid diet) per daily food diaries and FFQ; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing: BP and fasting blood lipids measured at baseline, day 25, and 28 | [underlined: LDL-C (mmol/L), Mean (SD), Baseline, post-intervention, Mean difference (95% CI)]; Palmitic acid: 3.51 (1.12), 3.58 (1.22); Stearic acid: 3.58 (1.12), 3.44 (1.14); Difference between Stearic acid vs. Palmitic acid: −0.14 (−0.24, −0.03), P=0.010; [underlined: HDL-C (mmol/L), Mean (SD), Baseline, post-intervention, Mean difference (95% CI)]; Palmitic acid: 1.48 (0.33), 1.48 (0.29); Stearic acid: 1.48 (0.34), 1.39 (0.27); Difference between Stearic acid vs. Palmitic acid: −0.09 (−0.12, −0.06), P<0.001; [underlined: TG (mmol/L), Mean (SD), Baseline, post-intervention, Mean difference (95% CI)]; Palmitic acid: 1.29 (0.63), 1.16 (0.57); Stearic acid: 1.19 (0.53), 1.24 (0.62); Difference between Stearic acid vs. Palmitic acid: 0.08 (−0.02, 0.18), P=0.100; [underlined: SBP (mmHg), Mean Difference (95% CI)]; Difference between palmitic acid and stearic acid: 0.4 (−1.9, 2.6), P=0.75; [underlined: DBP (mmHg), Mean Difference (95%CI)]; Difference between palmitic acid and stearic acid: 0.4 (−0.9, 1.7), P=0.52 | Key confounders: NA; Other covariates accounted for: Baseline values of both the corresponding period, average baseline of both periods; Limitations: Intervention oils are blends of two oils.; Funding: Unilever R&D Vlaardingen

a Abbreviations: %E: percent of energy; BMI: body mass index; BP: blood pressure; CHO: carbohydrate; CI: confidence interval; DBP: diastolic blood pressure; dL: deciliter; EVOO: extra virgin olive oil; FFQ: food frequency questionnaire; g: gram; HDL-C: high density lipoprotein cholesterol; kg: kilogram; LDL-C: low density lipoprotein cholesterol; m: meter; mg: milligram; mmol/l: millimoles per liter; MUFA: monounsaturated fatty acid; NA: not applicable; NR: not reported; NS: non-significant; PHSO: partially hydrogenated soybean oil; POL: palm olein; PRO: protein; PUFA: polyunsaturated fatty acid; RCT: randomized controlled trial; SBP: systolic blood pressure; SD: standard deviation; SEP: socioeconomic position; SFA: saturated fatty acid; TC: total cholesterol; TG: triglycerides; vs: versus; wk: week; y: year

Table 83 Risk of bias for randomized controlled trials on plant sources higher in saturated fat compared to a different food source of saturated fat in adults and older adults and risk of cardiovascular disease^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Cheng, 2019^91^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Cox, 1998^8^ | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Loganathan, 2022^96^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Stonehouse, 2020^100^ | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Sundram, 2007^102^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
van Rooijen, 2021^104^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 84 Evidence examining the relationship between plant sources higher in saturated fats compared to a food source of carbohydrate or protein in adults and older adults and risk of cardiovascular disease^a^

Study and Participant Characteristics | Intervention, Comparator, and Outcome | Results | Methodological Considerations
Chinwong, 2017^92^; RCT-crossover, Thailand; Analytic N = 32; Adequately powered: No; Study aims: To investigate the effect of daily virgin coconut oil consumption on plasma lipoproteins levels and document any adverse effects; Participant characteristics:; - Age: 21 (0.74) y; - Female: 50%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 20.8 (3.43) kg/m2; - Health Status: Healthy; Excluded those <18 y or >25 y, allergic to study foods, taking any medications, having related biomedical parameters outside of the normal range, unwilling to follow study protocols, who were pregnant | Intervention and comparators:; - Coconut oil (virgin): 15 mL, twice daily; SFA 86.4%, MUFA (oleic acid) 5.9%, PUFA (linoleic acid (C18:2n6)) 0.9%; - Carboxymethylcellulose (CMC), 2%: 15 mL, twice daily; Intervention duration: 8 wk (8 wk washout); Other group differences: Dietary intake: NR; Compliance: Assessed via study diary but NR; Outcome(s): LDL-C, HDL-C, TG, SBP, DBP; Outcome assessment methods and timing: Fasting blood lipids and BP measured before and after each diet period | [underlined: LDL-C (mg/dl), Mean change (SD), (before, after)]; Coconut oil: −6.08 (17.65), (116.6, 110.5); 2% CMC: −6.21 (16.04), (116.4, 110.2); Difference in change: 0.13 (21.16); p-change=0.972; [underlined: HDL-C (mg/dl), Mean change (SD), (before, after)]; Coconut oil: 3.91 (6.34), (60.3, 64.2); 2% CMC: −1.81 (6.49), (60.8, 59.0); Difference in change: 5.72 (9.01); p-change=0.001; [underlined: TG (mg/dl), Mean change (SD), (before, after)]; Coconut oil: −3.06 (24.07), (67.8, 64.7); 2% CMC: 3.06 (25.00), (69.3, 72.3); Difference in change: −6.13 (32.70); p-change=0.298; [underlined: SBP (mmHg), Mean change (SD), (before, after)]; Coconut oil: 0.50 (9.28), (114.3, 114.8); 2% CMC: 1.81 (7.61), (115.8, 117.6); Difference in change: −1.31 (10.52); p-change=0.485; [underlined: DBP (mmHg), Mean change (SD), (before, after)]; Coconut oil: −0.78 (9.24), (71.2, 70.4); 2% CMC: −1.78 (12.60), (71.3, 69.5); Difference in change: 1.00 (16.91); p-change=0.740 | Key confounders: NA; Other covariates accounted for: None; Limitations: Randomization methods NR; No preregistered protocol; Funding: Thailand Research Fund
Ekanayaka, 2013^93^; RCT-crossover, Sri Lanka; Analytic N = 60; Adequately powered: NR; Study aims: To study the effects of “natural” coconut milk and soya milk supplementation in “healthy” free living Sri Lankans who were consuming a customary “usual” Sri Lankan diet.; Participant characteristics:; - Age: 42.6 (10.3) y; - Female: 48%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: ~19.5 kg/m2; - Health Status: Healthy, all female participants were premenopausal; Excluded those who were not regular porridge consumers or consumed a diet atypical of the Sri Lankan diet, with physical complaints or were taking medications | Intervention and comparators:; - Coconut milk porridge: 36 g of coconut milk powder/200 ml, 260kcal, 9g CHO, 2.5 g PRO, 23 g FAT; 81.2% SFA, 6.0% MUFA (oleic acid), 1.7% PUFA; - Soya milk porridge: 52 g of soya milk powder/200 ml, 260kcal, 17g CHO, 15 g PRO, 15 g FAT; 15.6% SFA, 23.1% MUFA, 61.3% PUFA; Intervention duration: 8 wk (2 wk washout); Other group differences: Dietary intake: NR; Compliance: NR; Outcome(s): LDL-C, HDL-C; Outcome assessment methods and timing: Fasting blood lipids measured before and after each intervention period | [underlined: LDL-C (mg/dL), Mean (SD) at baseline, after intervention, Difference]; Coconut milk porridge: 133.9 (30.1), 119.0 (52.3); −11.8, p=0.02; Soy milk porridge: 139.3 (47.3), 127.5 (51.5); −14.9, p=0.09; Coconut milk vs soy milk porridge: p=NS; [underlined: HDL-C (mg/dL), Mean (SD) at baseline, after intervention, Difference]; Coconut milk porridge: 43.1 (6.6), 52.7 (13.3); 9.6, p<0.01; Soy milk porridge: 50.4 (9.1), 52.2 (11.0); 1.8, p=0.18; Coconut milk vs soy milk porridge: p<0.01 | Key confounders: NA; Other covariates accounted for: Baseline values; Limitations: Randomization methods NR; Did not account for period effects in analysis or design; No information about background diet or compliance provided; No preregistered protocol; Funding: Medical Research Institute of Colombo, Sri Lanka

a Abbreviations: BMI: body mass index; CMC: carboxymethylcellulose; DBP: diastolic blood pressure; dL: deciliter; g: grams; HDL-C: high density lipoprotein cholesterol; kg: kilogram; LDL-C: low density lipoprotein cholesterol; m: meter; mg: milligram; ml: milliliter; mmHg: millimeters of mercury; MUFA: monounsaturated fatty acid; NA: not applicable; NR: not reported; NS: non-significant; PUFA: polyunsaturated fatty acid; RCT: randomized controlled trial; SBP: systolic blood pressure; SD: standard deviation; SEP: socioeconomic position; SFA: saturated fatty acid; TG: triglycerides; vs: versus; wk: week; y: year

Table 85 Risk of bias for randomized controlled trials on plant sources higher in saturated fat compared to a food source of carbohydrate or protein in adults and older adults and risk of cardiovascular disease^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Chinwong, 2017^92^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Ekanayaka, 2013^93^ | HIGH | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )