# Results

## Literature search and screening results

The literature search (Appendix 2) yielded 35,899 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 30,211 titles, 2,913 abstracts, and 2,671 full-texts articles. Reasons for full-text exclusion are in Appendix 3. No additional articles were identified from the manual search. The body of evidence included 104 articles. Some articles include data for more than one of these categories:

- Children and adolescents
  ○ Dairy sources of saturated fat: 5 articles^1–5^
  ○ Meat sources of saturated fat: 0 articles
  ○ Plant sources of saturated fat: 0 articles
- Adults and older adults
  ○ Dairy sources of saturated fat: 48 articles^1,6–52^
  ○ Dairy sources of saturated fat compared to meat sources of saturated fat: 7 articles^34,38,53–57^
  ○ Meat sources of saturated fat: 39 articles^34,38,53–89^
  ○ Plant sources of saturated fat: 16 articles^8,90–104^

Figure 2 Literature search and screen flowchart

The literature searches in PubMed, Embase, and Cochrane retrieved 35,899 records after removing duplicates. No articles were found with manual search methods. 30,211 titles, 2.913 abstracts, and 2,671 full-texts were excluded. 104 articles were included in the systematic review.

## Children and adolescents

### Dairy sources of saturated fat

#### Description of the evidence

Five articles examined the relationship between dairy and dairy product consumption in children and risk of CVD,^1–5^ including 4 randomized controlled trials (RCT)^1–3,5^ (RCT-crossover,^1,2^ cluster^3,5^) and 1 prospective cohort study (PCS).^4^ Evidence from dairy and dairy product consumption and risk of CVD in children is summarized in Table 30. Risk of bias assessments are summarized in Table 31 (RCT) and Table 32 (observational studies).

##### Population

The 5 articles included children with a mean age ranging from 3 years^4^ to 12 years.^1^ Among the 4 articles that reported sex, all had similar proportions,^1–4^ though sex was not reported in one article.^5^ The sample sizes ranged from N=88^2^ to N=448^4^ in the trials and N=796 in the PCS.^4^

Studies were conducted in the following countries:

○ United States, 2 articles^1,4^
○ Australia, 1 article^3^
○ Mexico, 1 article^5^
○ Spain, 1 article^2^

Race and/or ethnicity was reported in 2 articles, and in both, the participants were predominantly or exclusively White.^1,4^ Socioeconomic position (SEP) was reported in 2 articles, and was determined based on maternal/paternal education and/or family income and was high in 1 article^4^ and medium in another.^3^ SEP was not reported in the other articles.^1,2,5^

##### Intervention/exposure and comparator

The intervention and exposure in this body of evidence included dairy products as a category,^3^ milk,^2,4,5^ or butter.^1^ The comparisons of interest in most of these studies focused on consumption of dairy products higher in total fat (e.g., whole milk, high-fat milk, regular-fat dairy) compared to consumption of dairy products with lower fat (e.g., partially defatted milk, low-fat milk, reduced low-fat dairy). One trial compared intake of butter (intervention) to intake of margarine as the comparator.^1^ Adherence to the intervention was reported in 2 trials,^1,3^ but was not reported in the other 2 trials.^2,5^ The trial duration ranged from 5 weeks^1^ to 7 months.^2^

A food frequency questionnaire (FFQ) was used to assess milk intake at baseline in the PCS.^4^ The follow-up duration in the PCS was ~10 years.^4^

##### Outcome

All articles assessed the effect of dairy consumption in children on fasting blood lipids.^1–5^ In addition, the PCS also assessed the association between milk consumption and systolic blood pressure assessed during early adolescent visit.^4^

#### Synthesis of the evidence

Results reported in this body of evidence were not consistent. Whole-fat milk compared to fat-free, defatted or partially defatted milk increased low-density lipoprotein cholesterol (LDL-C) levels in 2 articles.^1^ The third article showed that LDL-C decreased at 24 weeks after parents were randomized to receive education on changing to reduced-fat dairy foods in their children’s diet (intervention group), while the comparator maintained habitual intake of regular fat dairy products.^2,5^ Most articles reported no effects on high-density lipoprotein cholesterol (HDL-C) or triglycerides of the intervention or comparator, with the exception of 1 article each for HDL-C^3^ and triglycerides.^3^ There was no association between high fat compared to low-fat milk and blood pressure.^4^ The trial^1^ that compared butter intake to margarine was not considered extensively since the intervention and comparators were slightly different than the rest of the evidence.

#### Conclusion statement and grade

The Committee was not able to develop a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on dairy sources of saturated fat in children and adolescents (Table 5). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, because many studies reported null findings, publication bias may not be a major concern.

Table 5 Conclusion statement and grade for dairy sources of saturated fat in children and adolescents and risk of cardiovascular disease

Conclusion Statement | A conclusion statement cannot be drawn about dairy sources of saturated fat and different comparators consumed by children and adolescents and the relationship with blood lipids or blood pressure because there is not enough evidence available. Comparators considered included similar food sources with different amounts of total fat; food sources of unsaturated fat, carbohydrate, or protein; or a different food source of saturated fat.
Grade | Grade Not Assignable
Body of Evidence | 4 articles: 3 RCT, 1 PCS
Rationale | - Some concerns with consistency with studies showing mixed findings.; - Substantial concerns with heterogeneity in the age range of the children, which corresponds to different requirements for dairy products.; - Serious concerns with generalizability, with lack of diversity of participants in the included articles.

### Meat sources of saturated fat

#### Description of the evidence

No articles examined the relationship between meat sources of saturated fat (e.g., red meat, white meat, processed meat) consumed by children and adolescents and risk of cardiovascular disease.

#### Conclusion statement and grade

The Committee was not able to develop a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on the lack of evidence to review meat sources of saturated fat in children and adolescents (Table 6).

Table 6 Conclusion statement and grade for meat sources of saturated fat in children and adolescents and risk of cardiovascular disease

Conclusion Statement | A conclusion statement cannot be drawn about meat sources of saturated fat (including red meat, processed meat, and white meat) and different comparators consumed by children and adolescents and the relationship with blood lipids or blood pressure because there is no evidence available. Comparators considered included similar food sources with different amounts of total fat; food sources of unsaturated fat, carbohydrate, or protein; or a different food source of saturated fat.
Grade | Grade Not Assignable
Body of Evidence | 0 articles
Rationale | There was no evidence available examining this relationship in children or adolescents.

### Plant sources of saturated fat

#### Description of the evidence

No articles examined the relationship between plant sources higher in saturated fat (e.g., palm oil, coconut oil, cocoa butter) consumed by children and adolescents and risk of cardiovascular disease.

#### Conclusion statement and grade

The Committee was not able to develop a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on the lack of evidence to review plant sources of saturated fat in children and adolescents (Table 7).

Table 7 Conclusion statement and grade for plant sources of saturated fat in children and adolescents and risk of cardiovascular disease

Conclusion Statement | A conclusion statement cannot be drawn about plant sources higher in saturated fat (such as palm oil, coconut oil, or cocoa butter) and different comparators consumed by children and adolescents and the relationship with blood lipids or blood pressure because there is no evidence available. Comparators considered included similar food sources with different amounts of total fat; food sources of unsaturated fat, carbohydrate, or protein; or a different food source of saturated fat.
Grade | Grade Not Assignable
Body of Evidence | 0 articles
Rationale | There was no evidence available examining this relationship in children or adolescents.

## Adults and older adults

### Dairy sources of saturated fat

The body of evidence examining dairy sources of saturated fat consumed by adults and older adults included 48 articles.^1,6–52^ Twenty-nine of these were RCT^1,6–33^ (21 RCT-crossover^1,6–25^ and 8 RCT-parallel^26–33^) and 19 were PCS.^34–52^

The intervention or exposure was consumption of dairy or dairy products (i.e., milk, yogurt, cheese, butter, buttermilk). The evidence assessing dairy sources of saturated fat consumed by adults and older adults was categorized based on 4 comparators: a similar food source with different amounts of saturated fat, a food source of unsaturated fatty acids, a food source of carbohydrate and/or protein, and a different dairy source of saturated fat. Some articles contributed data to more than one category.

#### Comparing dairy with different amounts of total fat

Fifteen articles examined the relationship between dairy with different amounts of saturated fatty acids due to different amounts of total fat and risk of CVD^25,28,31,35,38–40,42–45,47,49,50,52^ and included 3 RCT (2 parallel RCT and 1 crossover RCT)^25,28,31^ and 12 PCS.^35,38–40,42–45,47,49,50,52^ Evidence comparing dairy with different amounts of total fat and risk of CVD in adults and older adults is summarized in Table 33. Risk of bias assessments for each article are summarized in Table 34 (RCT) and Table 35 (observational studies).

##### Description of the evidence

###### Population

Fourteen articles enrolled adults^25,28,31,35,38,39,42–45,47,49,50,52^ and 1 enrolled older adults.^40^ Mean or median age of the participants ranged from ~40 to 65 years in most articles, although 1 article enrolled young adults with a mean age of 19 years^25^ and another reported a median age of 75 years.^40^ Sample sizes ranged from N=45^25^ to N=80,082.^52^

Studies were conducted in the following countries:

○ Denmark, 4 articles^31,42,43,45^
○ United States, 4 articles^25,38,50,52^
○ Australia, 2 articles^40,47^
○ Netherlands, 2 articles^35,44^
○ Sweden, 2 articles^39,49^
○ Norway, 1 article^28^

Participants were generally healthy, though mean BMI of the participants was ≥25 kg/m^2^ in more than half of the articles.^28,31,35,38,39,42–45,47,50^ Raziani et al^31^ enrolled only those participants with more than two metabolic syndrome risk factors.

Race and/or ethnicity of the study participants was not reported in most of the articles.^25,28,31,35,39,40,42–45,47,49^ The articles that reported race and/or ethnicity noted that the participants were predominantly or exclusively White.^38,50^ Regarding SEP of the participants, 2 articles reported that more than half of the participants had low educational attainment^38,44^ whereas one article exclusively enrolled nurses.^52^ Most of the articles could be classified as having medium SEP, based on family income and/or education.^3,25,28,35,42,43,45,47,49,50^ In addition to these, one article was classified as high SEP^52^ and another one had low SEP,^44^ while three other articles did not report information on SEP.^31,39,40^

###### Intervention/exposure and comparator

The intervention or exposure examined in this body of evidence included dairy as a category^25,35,38,39,47,52^ or individual types of dairy such as milk,^40,42–45,49,50^ cheese,^28,31,49^ and yogurt.^42–45,49^ The comparisons of interest focused on the consumption of dairy products higher in total fat versus consumption of dairy products lower in total fat.

Two trials compared regular-fat cheese intake to reduced-fat or low-fat cheese intake.^28,31^ Another trial compared whole-fat to low-fat dairy in a crossover trial.^25^ All trials reported compliance to the assigned intervention, which was reported to be >95% in 2 articles. Some trials reported information on other dietary components at baseline and follow-up, but there were no noteworthy differences between the diets. The intervention duration for the trials ranged between 8 weeks^25,28^ and 12 weeks.^31^

Many of the PCS were substitution studies, which involved conducting analyses to estimate the association between substituting whole-fat with low-fat dairy products. PCS typically used a FFQ to assess the intake of dairy and dairy products.^35,38,39,42–45,47,49^ Most articles assessed exposure at a single time-point, mostly at baseline and one article collected dietary information at multiple timepoints.^52^ The duration of follow-up ranged from ~4 years^40^ up to ~22 years in the observational studies.^38^

###### Outcome

Two trials measured fasting blood lipids^28,31^ and 3 trials measured blood pressure.^25,28,31^ Nine PCS measured CVD morbidity,^35,38–40,42–44,49,52^ which included major vascular events,^40^ stroke,^43,44^ composite of non-fatal and fatal coronary heart disease (CHD),^35,38,39^ non-fatal and/or fatal myocardial infarction, non-fatal myocardial infarction or fatal coronary disease.^42,49,52^ Three PCS assessed the risk of CVD mortality.^45,47,50^ Data on CVD morbidity and CVD mortality were collected from hospital records,^35,40,49^ national patient registries^39,42,43^ and death certificates,^38^ death registries.^39,42,45,47,49,50,52^ Some of the CVD morbidity data was also adjudicated by a physician.^35,38,40,52^

##### Synthesis of the evidence

###### Blood lipids and blood pressure

Two trials that tested the effects of consuming high-fat compared to low-fat cheese reported no differences in blood lipids between groups.^28,31^ Similarly, the 3 trials that assessed the effect of dairy and cheese, compared to lower varieties, on blood pressure also showed no effect.^25,28,31^

###### CVD morbidity

Most of the PCS that compared high-fat to low-fat dairy/dairy products and CVD morbidity reported no associations. A few articles reported significant or trending associations in different directions. For example, 1 PCS reported decreased risk of CVD morbidity among those that consumed high-fat dairy, compared to those that consumed low-fat dairy.^39^ The same article also reported a trend for lower risk of CVD morbidity with high-fat milk compared to low-fat milk.^39^ Another study reported that consuming whole-fat yogurt compared to low-fat yogurt showed a trend towards lower risk of ischemic stroke morbidity.^44^ In contrast, another PCS reported an increased risk of major vascular events in those that consumed full-fat milk compared to reduced-fat or skim milk,^40^ while another reported a significant trend for greater risk of coronary heart disease with higher quintiles of high-fat to low-fat dairy product ratio.^52^

###### CVD mortality

One article^50^ showed that whole-fat milk was associated with greater risk of CVD mortality, compared to 2% and ≤1% milk; however, the other 2 articles reported null findings.^45,47^

##### Conclusion statement and grade

The Committee developed 2 conclusion statements to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on dairy with different amounts of saturated fatty acids due to different amounts of total fat by adults and older adults (Table 8).

Table 8 Conclusion statements and grades for dairy with different amounts of saturated fatty acids due to different amounts of total fat by adults and older adults and risk of cardiovascular disease

Conclusion Statement | Substituting higher-fat dairy with lower-fat dairy by adults and older adults is not associated with a difference in risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as limited. | A conclusion statement cannot be drawn about the relationship between higher-fat dairy consumption, compared to their lower-fat versions, by adults and older adults and blood lipids, blood pressure and cardiovascular disease mortality because there is not enough evidence available.
Grade | Limited | Grade Not Assignable
Body of Evidence | 9 articles (all PCS); 15 comparisons | 6 articles: 3 RCT, 3 PCS
Consistency | Some concerns with most studies consistently showing no association. | Rationale:; - Substantial concerns with consistency in findings across studies in this smaller body of evidence.; - Some concerns with risk of bias with issues due to potential exposure measurement error.; - Serious concerns with generalizability, with most of the studies included in this body of evidence were not conducted in the U.S.
Precision | Some concerns with precision. Sample sizes were large, and confidence intervals were narrow.
Risk of bias | Some concerns with risk of bias, mainly due to issues with confounding, exposure assessment and selection of reported results.
Directness | Some concerns with directness with populations, intervention/exposure, comparators, and outcomes were directly related to the systematic review question in most studies.
Generalizability | Serious concerns with most studies conducted in non-U.S. settings. Race and/or ethnicity and SEP was not reported in most articles.

###### Assessment of the evidence

This body of evidence included 9 articles that met the inclusion criteria and examined dairy with different amounts of saturated fatty acids due to different amounts of total fat and risk of CVD morbidity. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, because many studies reported null findings, publication bias may not be a major concern.

###### Consistency

There were few concerns with consistency, as most of the studies in this body of evidence consistently showed no difference in the risk of CVD morbidity when consuming high-fat compared to lower-fat dairy and dairy products. These results were noted for dairy as well as specific types of dairy products such as milk, cheese and yogurt. The findings persisted across studies, irrespective of the duration of follow-up, which was typically >10 years for PCS. The only exceptions were two PCS that demonstrated an increased risk of CVD morbidity with higher-fat dairy or dairy products.

###### Precision

There were some concerns with precision in this body of evidence. All of the articles were PCS, with no data from the trials. Most of the articles, except 2, had more than 10,000 participants, and those 2 articles had 787 and 1752 participants. Studies also reported minimal variance, as evidenced by the relatively narrow confidence intervals.

###### Risk of bias

There were serious concerns with risk of bias. Confounding was an issue, with articles not accounting for multiple key confounders resulting in high or very high risk of bias for this domain. Some articles lacked sensitivity in the way that the exposure was measured and reported. Often times, studies combined low-fat dairy (e.g.,1%, 2% dairy products) as one group and rarely gave additional details about the individual fat percentage of the dairy products. Studies did not have a pre-specified analysis plan, which resulted in concerns with the selection of reported results.

###### Directness

There were some concerns with directness since many of the included articles were substitution studies. The included articles, however, addressed the research question, as they used data from a larger cohort that intended to examine relationships between diet and health.

###### Generalizability

There were serious concerns with generalizability. All but 2studies were conducted in non-U.S. settings. Race and/or ethnicity was not reported in most studies, except two studies that noted that most of the participants were White. SEP was categorized as high, medium or low.

#### Dairy compared to food sources of unsaturated fatty acids

Seven articles, including 2 RCT^6,13^ and 5 PCS^34,36–38,48^ compared dairy to food sources of unsaturated fatty acids (i.e., mono- or polyunsaturated fatty acids (MUFA/PUFA)) and risk of CVD.^6,13,34,36–38,48^ Evidence comparing dairy to food sources of unsaturated fatty acids and risk of CVD in adults and older adults is summarized in Table 36. Risk of bias assessments for each article are summarized in Table 37 (RCT) and Table 38 (observational studies).

##### Description of the evidence

###### Population

All articles enrolled adults and older adults. The mean age of the participants was generally in the range of 50 to 60 years, with the exception of 1 reporting the mean age as ~39 years^6^ and another ~65 years.^37^ Most articles enrolled similar proportions of men and women, while 1 article included 100% female participants.^34^ The sample sizes ranged between N=31^13^ and N=110,487^48^ participants.

Studies were conducted in the following countries:

○ United States, 5 articles^34,36–38,48^
○ Canada, 1 article^6^
○ Finland, 1 article^13^

One trial exclusively enrolled participants with elevated cholesterol (mild to moderate)^13^ and another trial exclusively enrolled participants with obesity.^6^ In the PCS, the mean BMI of the participants was >25 kg/m^2^, however, the participants were generally healthy. Race and/or ethnicity was reported in all articles, except one^13^ and reported that the participants were predominantly or exclusively White. Based on education and/or profession, SEP for 4 articles was categorized as high,^34,36,37,48^ low in 1^38^ and not reported in the 2 trials.^6,13^

###### Intervention/exposure and comparator

The intervention or exposure included dairy and cheese. The comparator was food sources of unsaturated fatty acids, including fish and/or seafood,^34,38^ nuts,^38^ olive oil,^36,37^ avocado,^48^ rapeseed oil-based cheese,^13^ and MUFA/PUFA diet rich in olive oil and corn oil.^6^

In a crossover trial, participants were randomized to milk-fat cheese condition (15.6 g of SFA) or rapeseed oil-based cheese (0.7 g of SFA) for 4 weeks.^13^ Another crossover trial randomized participants to a diet rich in saturated fats from cheese (12.6 g of SFA) condition or other conditions such as diets rich in MUFA, primarily from refined olive oil (5.8 g of SFA) and PUFA, primarily from corn oil (5.8 g of SFA).^6^

In PCS, validated FFQs were used to assess the intake of dairy and dairy products. PCS assessed diet at baseline followed by at least one assessment at 6 years or periodic assessments every 3-4 years. The articles assessed cumulative intake, which was used as the exposure. All PCS conducted substitution analyses, where dairy was replaced with different food sources of unsaturated fatty acid, including fish or olive oil or nuts or avocado.

###### Outcome

Two trials assessed fasting blood lipids and blood pressure.^6,13^ Four articles assessed the association between dairy, when substituted with olive oil, fish, nuts, avocado and risk of CVD morbidity.^34,37,38,48^ CVD morbidity outcomes included CHD,^34,38,48^ CVD^48^ and stroke.^37,48^ One article assessed the association between dairy consumption, when substituted with olive oil, and CVD mortality.^36^ CVD morbidity and mortality was ascertained using medical records,^34^ medical reports,^36–38^ death certificates^36–38^ and the information was adjudicated by physicians in most of the articles.^36–38,48^ The duration of follow-up ranged from 22 years^38^ to 30 years.^48^

##### Synthesis of the evidence

###### Blood lipids and blood pressure

Two trials examined the effect of cheese compared to food sources of unsaturated fatty acids on blood lipids and blood pressure.^6,13^ In both trials, the cheese condition had higher LDL-C than the comparator. While HDL-C increased in one trial,^6^ there was no effect in the other.^13^ Similarly, there were no effects on triglycerides and blood pressure.

###### CVD morbidity

The body of evidence on dairy and cheese compared to food sources of unsaturated fatty acids was generally consistent. Four articles reported that substituting dairy and cheese with food sources of unsaturated fatty acids was associated with a decreased risk of CVD morbidity.^34,37,38,48^ One of these articles noted that substituting high-fat dairy with fish was associated with a lower risk of CVD morbidity, whereas, there was no association when low-fat dairy was substituted with fish.^34^ Another PCS noted that high-fat or low-fat dairy when substituted with fish/seafood was not associated with CVD morbidity. The same study noted a tendency towards greater risk of CVD morbidity in high-fat dairy compared to nuts, and no association between low-fat dairy compared to nuts.^38^

###### CVD mortality

Only one article assessed CVD mortality, reporting that substituting dairy consumption for olive oil was associated with an increased risk of CVD mortality.^36^

##### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on dairy consumption compared to unsaturated fatty acids by adults and older adults (Table 9).

Table 9 Conclusion statement and grade for dairy compared to food sources of unsaturated fatty acid intake and risk of cardiovascular disease

Conclusion Statement | Substituting dairy with food sources of unsaturated fatty acids by adults and older adults may be associated with a lower risk of cardiovascular disease. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 7 articles (2 RCT and 5 PCS); 11 comparisons
Consistency | Some concerns with consistency with most studies reporting a pattern of reduced CVD risk when substituting dairy with food sources of unsaturated fatty acids.
Precision | Serious concerns with precision. The trials had smaller sample sizes and one of them did not report power calculations. The PCS had adequate sample sizes and results with narrow confidence intervals.
Risk of bias | Some concerns with risk of bias, due to confounding, selection of reported results, exposure measurement and missing data in a few articles.
Directness | Some concerns with directness. Although most studies used substitution analyses, the populations, intervention/exposure, comparators, and outcomes were directly related to the systematic review question in most studies.
Generalizability | Serious concerns with generalizability. Although many studies were conducted in the U.S., participants enrolled had limited diversity in race/ethnicity and socioeconomic position.

###### Assessment of the evidence

This body of evidence included 7 articles that examined dairy compared to food sources of unsaturated fatty acids and risk of CVD. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, because some studies reported null findings, publication bias may not be a major concern.

###### Consistency

There were some concerns with consistency as most of the articles noted lower risk of CVD when dairy and cheese were substituted with a food source of unsaturated fatty acid. The findings were consistent across the intervention or exposure, comparator (which included fish, olive oil, rapeseed oil or diet rich in MUFA/PUFA), duration of the intervention, and duration of follow-up in PCS.

###### Precision

There were serious concerns with precision. The trials had small sample sizes, and one of them did not report power calculations. The PCS had adequate sample sizes and results with narrow confidence intervals.

###### Risk of bias

There were some concerns with risk of bias. Most trials had minimal information regarding randomization procedures. Missing data were an issue in a few PCS, since complete data were not available for all participants, or some articles provided minimal information on those who were included or excluded from analyses. Studies did not have a pre-specified analysis plan or protocol, which resulted in concerns with the selection of reported results.

###### Directness

There were some concerns with directness mainly because the PCS used substitution analyses. However, the PCS still addressed the research question, as they used data from a larger cohort that intended to examine relationships between diet and health. The trials directly assessed the intervention, comparator and outcomes of interest.

###### Generalizability

There were serious concerns with generalizability because of the lack of diversity in the participants. Studies generally included participants who were predominantly or exclusively White. The trials did not report SEP; most of the PCS included participants with high SEP, and only one article included participants with low SEP.

#### Butter compared to food sources of unsaturated fatty acids

Eighteen articles compared intake of butter as a food source of saturated fat to food sources of unsaturated fatty acids (i.e., MUFA/PUFA) by adults and older adults.^1,6–8,10,12,15,18,19,21,24,27,36,37,39,46,48,51^ Twelve articles were trials (11 RCT-crossover^1,6–8,10,12,15,18,19,21,24^ and 1 RCT-parallel^1,6–8,10,12,15,18,19,21,24,27^) and 6 articles were PCS.^36,37,39,46,48,51^ Evidence comparing butter to food sources of unsaturated fatty acids and risk of CVD in adults and older adults is summarized in Table 39. Risk of bias assessments for each article are summarized in Table 40 (RCT), and Table 41 (observational studies).

##### Description of the evidence

###### Population

Eighteen articles were conducted in adults and older adults. Mean or median age of the participants ranged between 35 and 65 years. Three articles exclusively enrolled male participants^21,24,39^ and 2 articles exclusively enrolled female participants.^19,46^ The rest of the articles was relatively balanced in terms of the sex of the participants. The sample sizes of the included articles ranged from N=30^18^ to N=521,120.^51^

Studies included in this body of evidence were conducted in the following countries:

○ United States, 9 articles^1,12,15,24,36,37,46,48,51^
○ Iran, 2 articles^18,27^
○ New Zealand, 2 articles^7,8^
○ Canada, 1 article^6^
○ Denmark, 1 article^10^
○ Finland, 1 article^21^
○ Spain, 1 article^19^
○ Sweden, 1 article^39^

One article exclusively enrolled participants with abdominal obesity^1,6^ and two articles exclusively enrolled participants with hypercholesterolemia.^7,15^ Most articles did not report race and/or ethnicity of the participants.^7,10,12,15,18,21,24,27,39^ Among those articles that reported race and/or ethnicity of study participants noted that they were predominantly or exclusively White.^1,6,19,36,37,46,48,51^ One article exclusively enrolled Pacific Islanders.^8^ Similarly, SEP was not commonly reported in the articles.^1,6–8,10,12,15,18,19,21,39^ Among those that did report education and/or income, 3 articles described participants as having high SEP^36,37,48^ and 4 articles included participants with medium SEP.^24,27,46,51^

###### Intervention/exposure and comparator

The intervention or exposure of interest in these studies was butter, and the comparators were food sources of unsaturated fatty acids (i.e., MUFA/PUFA). Many studies that examined food sources of unsaturated fat as a comparator were RCT^1,6–8,10,12,15,18,19,21,24,27^ in which participants consumed butter in one condition and a food source of unsaturated fatty acids, such as olive oil, safflower oil, rapeseed oil, or margarine, in the other condition. In addition, this body of evidence included PCS that conducted analyses in which butter was replaced with 1 or more of the following: margarine, avocado, olive oil, corn and canola oil.^36,37,39,46,48,51^

In the trials, intervention duration ranged between 4 weeks^6^ and 12 weeks.^24^ While the adherence was not reported in a few trials,^8,19,21^ many noted that participants were generally adherent to study protocols.^1,6,7,10,12,15,18,24^ In addition, many trials reported that aside from the butter and the food sources of MUFA/PUFA, other aspects of diet did not differ between groups at baseline and follow-up.

In the PCS, the duration of follow-up ranged from ~12 years^39^ up to ~30 years.^48^ Validated FFQs were used to assess the intake of butter in the PCS. While some studies used a single time-point measurement,^39,51^ others assessed diet every 3-4 years and used a cumulative intake as the exposure.^36,37,46,48^

###### Outcome

Twelve articles assessed fasting blood lipids^1,6–8,10,12,15,18,19,21,24,27^ and 3 articles assessed blood pressure.^6,18,21^ Two articles assessed CVD mortality^36,51^ and 7 articles assessed CVD morbidity,^37,39,42–44,46,48^ which included stroke,^37,43,44^ myocardial infarction,^42,46^ total CHD,^37,39,46,48^ and total CVD.^37^ Morbidity data was collected from medical records^37,46^ and patient registries,^39,42–44^ which was adjudicated in some studies. Mortality was assessed using death certificates, autopsy reports, or linkages to Social Security Administration Death Master File.^36,51^

##### Synthesis of the evidence

###### Blood lipids and blood pressure

Most trials consistently reported that LDL-C levels increased in butter consumers, irrespective of the food source of unsaturated fatty acids consumed as the comparator.^1,6–8,10,12,15,19,21,24^ One additional trial compared ghee vs. hydrogenated oil, which showed a null effect.^27^

The majority of the studies reported no difference in HDL-C between the conditions in which participants consumed butter compared to the conditions in which a food source of unsaturated fatty acids was consumed.^1,6,7,10,12,18,19,21,24,27^ Only 2 of the 12 trials^8,15^ reported an increase in HDL-C in the butter condition, in comparison to safflower oil^8^ and stick margarine.^15^ The latter trial also showed an increase in HDL-C when compared to shortening, but only in women.^15^

Most trials did not report a difference in triglyceride levels between butter and comparator groups.^6–8,10,12,15,18,19,21,24,27^ The only exceptions were Mohammadifard et al^27^ that reported reduced triglycerides in ghee compared to hydrogenated oil, and Denke et al^1^ that reported increased triglycerides in the butter group, when compared to margarine.

None of the trials showed an effect of consuming butter compared to a food source of unsaturated fatty acids on systolic and diastolic blood pressure.^6,18,21^ Considering that the lack of known biological mechanism for the relationship between butter consumption and blood pressure, a conclusion statement was not drawn about this relationship.

###### CVD morbidity

Results showed an increased risk of CVD and CHD when butter was substituted with food sources of unsaturated fatty acids, including avocado^48^ and olive oil, ^36,37^ and null associations when butter was compared to margarine.^39,46^ In one study, butter was associated with increased CVD and CHD risk, when substituted for avocado intake.^48^ Similarly, butter was associated with greater CVD morbidity when substituted with olive oil in 2 articles.^36,37^

###### CVD mortality

One study conducted substitution analyses in which butter was replaced with olive oil, canola oil, corn oil, and margarine.^51^ The study showed significant increased risk of CVD mortality for butter compared to olive oil and canola oil, and a non-significant increase in risk compared to corn oil. CVD mortality risk did not differ between butter and margarine.

##### Conclusion statements and grades

The Committee developed 2 conclusion statements to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on butter compared to food sources of unsaturated fats by adults and older adults (Table 10).

Table 10 Conclusion statements and grades for butter consumption by adults and older adults compared to a food source of unsaturated fatty acids and risk of cardiovascular disease

Conclusion Statement | Replacing butter with plant-based oils and spreads, with predominantly unsaturated fatty acids, by adults and older adults decreases LDL-C levels, but does not affect HDL-C or triglyceride levels. This conclusion statement is based on evidence graded as strong. | Substituting butter with plant-based oils and spreads, with predominantly unsaturated fatty acids, by adults and older adults may be associated with a decreased risk of cardiovascular disease morbidity and mortality. This conclusion statement is based on evidence graded as limited.
Grade | Strong | Limited
Body of Evidence | 12 RCT (11 RCT-crossover, 1 RCT-parallel); 21 comparisons | 6 PCS; 12 comparisons
Consistency | Few concerns with consistency. Almost all trials demonstrated consistent effects on decreasing LDL-C levels, and no effects on HDL-C and triglycerides with replacement of butter with plant-based oils and spreads. | Substantial concerns with consistency with studies reporting heterogeneous findings. Yet, studies showed a pattern of reduced risk for CVD morbidity and mortality, when substituting butter with plant-based oils and spreads rich in MUFA/PUFA.
Precision | Few concerns with precision. Trials demonstrated adequate power/sample sizes and reported results with narrow confidence intervals. | Some concerns with precision with studies having large sample sizes and narrow confidence intervals.
Risk of bias | Some concerns with risk of bias due to a lack of information about randomization methods and the potential for selective reporting of results. | Some concerns with risk of bias due to selection of reported results, and missing data in a few articles.
Directness | Few concerns with directness. The studies were designed to examine the effects of butter compared food sources of saturated fatty acids on risk of cardiovascular disease in adults. | Some concerns with directness primarily due to modeling approach used in the substitution analyses.
Generalizability | Serious concerns with generalizability since a majority of the trials were not conducted in the U.S. | Serious concerns with generalizability. Although most studies included U.S. participants, there was limited diversity in race/ethnicity and socioeconomic position.

###### Assessment of the evidence: Replacing butter with plant-based oils and spreads

The body of evidence included 12 trials that examined the effect on blood lipids when butter intake was replaced with plant-based oils and spreads with predominantly unsaturated fatty acids and blood lipids. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, because few studies reported null findings, publication bias may be of concern.

###### Consistency

There were few concerns with consistency. The body of evidence included strong study designs with consistent findings in direction and effect. LDL-C levels increased consistently with butter intake compared to intake of food sources of unsaturated fatty acids, whereas there was no effect on HDL-C and triglycerides across most of the trials. This effect was noted irrespective of the different comparators across studies, which included olive oil, safflower oil, rapeseed oil and margarine. The findings were also consistent across different intervention durations, which ranged between 4 and 12 weeks. Similarly, the effect of butter intake on LDL-C and lack thereof for HDL-C and triglycerides, were noted consistently irrespective of participant’s health status (healthy, 100% participants with hypercholesterolemia, metabolic syndrome and obesity).

###### Precision

There were few concerns with precision. Most trials included about 50-100 participants and some articles reported power calculations and were adequately powered. Studies also reported minimal variance, as evidenced by the relatively narrow confidence intervals.

###### Risk of bias

There were some concerns with risk of bias for most studies surrounding lack of details regarding randomization and concealment methods and having no pre-registered data analysis plans increasing the potential for selective reporting of results. Few studies had some concerns with deviations from the intended interventions or missingness of the outcome data.

###### Directness

There were few concerns with directness with most of the trials directly designed to examine the effects of butter compared to food sources of unsaturated fatty acids on risk of CVD in adults and older adults.

###### Generalizability

There were substantial concerns with generalizability, given that only four trials were conducted in the U.S. and the rest were conducted in New Zealand, Iran, Denmark, Spain and Finland. Few articles described race and/or ethnicity of participants. Of those that did, three articles included predominantly or exclusively White participants and one exclusively enrolled Pacific Islanders. SEP was mostly not reported in the trials, although few reported having participants with medium SEP.

###### Assessment of the evidence: Substituting butter with plant-based oils and spreads

The body of evidence included 6 PCS that met inclusion criteria and examined the association of substituting butter intake with plant-based oils and spreads, with predominantly unsaturated fatty acids, on risk of CVD morbidity and mortality. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, because a few studies reported null findings, publication bias may not be a major concern.

###### Consistency

There were substantial concerns with consistency. Despite heterogeneity, some articles showed decreased risk of CVD morbidity and mortality when substituting butter with plant-based oils and spreads rich in unsaturated fatty acids. Most of these were substitution articles that substituted butter intake with one or more of the following comparators: olive oil, corn oil, and avocado. Studies that compared butter to margarine showed no difference in CVD morbidity and mortality. However, the results of the remaining studies with other comparators were trending or significantly associated with lower risk of CVD morbidity and mortality.

###### Precision

There were some concerns with precision as this was a relatively smaller body of evidence. However, all of the articles had more than 1000 participants and 2 articles had greater than 100,000 participants. Studies also reported minimal variance, as evidenced by the relatively narrow confidence intervals.

###### Risk of bias

There were some concerns with risk of bias. Most of the included articles did not have a pre-specified analysis plan, which resulted in concerns with risk of bias for selection of reported results. Although key confounders were consistently accounted for in most articles, 1 article^39^ had a very high risk of bias, since none of the key confounders except sex were accounted for. Missing data were an issue in a few articles, since complete data were not available for all participants, or some articles provided minimal information on who were included/excluded from the analysis.

###### Directness

There were some concerns with directness since most of them were substitution studies. However, they addressed the research question, as they used data from a larger cohort that intended to examine relationships between diet and health.

###### Generalizability

There were substantial concerns with generalizability. Although most studies were conducted in the U.S., there was limited diversity. Participants in the included articles were predominantly or exclusively White. Studies also included participants with medium or high SEP. The median age of the participants across included articles were ~63 y and were generally healthy.

#### Substituting or replacing one form of dairy with another form of dairy

Ten articles examined the intake of one form of dairy compared with another form of dairy and risk of CVD.^6,11,20,30,32,33,42–45^ Six of the articles were RCT^6,11,20,30,32,33^ and 4 were PCS.^42–45^ Evidence comparing one form of dairy with another form and risk of CVD in adults and older adults is summarized in Table 42. Risk of bias assessments for each article are summarized in Table 43 (RCT) and Table 44 (observational studies).

##### Description of the evidence

###### Population

All 10 articles were conducted in adults and older adults.^6,11,20,30,32,33,42–45^ Mean or median age of the participants ranged between ~40 and 60 years. While most studies included similar proportions of males and females, few articles had a majority of female participants^30,44^ and 1 article had a majority of male participants.^20^ Sample sizes in the trials ranged between N=19^20^ and 156,^32^ while the sample sizes in the PCS ranged between N=36,886^44^ and N=55,775.^45^

Studies included in this body of evidence were conducted in the following countries:

○ Denmark, 4 articles^11,42,43,45^
○ Australia, 1 article^20^
○ Canada, 1 article^6^
○ France, 1 article^32^
○ Netherlands, 1 article^44^
○ Sweden, 1 article^33^
○ Thailand, 1 article^30^

Although participants were generally healthy, 2 trials exclusively enrolled participants with hypercholesterolemia.^20,32^ Three articles exclusively enrolled participants with overweight and/or obesity, and one exclusively included participants with abdominal obesity.^6,20,32,33^ Race and/or ethnicity was not reported in most of the articles. However, 1 article noted that the participants were predominantly White^6^ and another article noted that all of the participants were Danish.^42^ SEP, based on income and/or education, was classified as medium in 3 PCS,^42,43,45^ and low in 1 PCS.^44^ The trials did not report SEP of the participants.^6,11,20,30,32,33^

###### Intervention/exposure and comparator

The intervention or exposure and comparisons of interest were one form of dairy compared to another form of dairy, including milk, yogurt, cheese, butter and buttermilk. Three crossover trials^6,11,20^ compared a cheese condition to a butter condition, and 1 parallel trial compared cheese and yogurt.^32^ The amount of saturated fat varied across studies ranging from 5.4 g to ~37 g SFA. One trial compared butter oil to whipping cream^33^ and another trial compared cow milk or goat milk.^30^ Both of these trials did not report saturated fat content in the intervention or comparator groups. The intervention duration in trials ranged between 4 weeks^6,20^ and 8 weeks.^33^ Most of the trials reported good compliance to the intervention and comparators.

PCS conducted multiple analyses that substituted cheese, butter, buttermilk, whole-fat, low-fat milk and yogurt with one another. For example, whole-fat milk was substituted with whole-fat yogurt, whole-fat fermented milk, semi-skimmed fermented milk, low-fat yogurt, cheese, butter and buttermilk.^42–45^ Similarly, low-fat yogurt was substituted for whole-fat milk, low-fat milk, buttermilk, butter and cheese.^42,44,45^ FFQs were assessed at baseline in all of the PCS and the follow-up duration ranged between 13.4 years^43^ to 19 years.^45^

###### Outcome

Six trials examined the effect of comparing one form of dairy with another form on fasting blood lipids and blood pressure.^6,11,20,30,32,33^ Three articles assessed the association between one form of dairy compared to another form and CVD morbidity^42–44^ and 1 article assessed CVD mortality.^45^ CVD morbidity outcomes included stroke,^43,44^ and myocardial infarction.^42^ CVD mortality was assessed using death registry,^45^ while morbidity was assessed using patient registries and hospital discharge diagnoses.^42–44^

##### Synthesis of the evidence

###### Blood lipids and blood pressure

Most studies reported null effects on blood lipids and blood pressure when replacing one form of dairy with another. The effects on LDL-C were mixed, with 3 studies showing null effects,^20,30,32^ and 2 studies showing lower LDL-C in the cheese^6^ or whipping cream^33^ groups compared to butter or butter and oil combined. There was no effect on blood pressure and HDL-C.^6,11,20,30,32^ One article showed an increase in triglycerides in the cheese condition compared to the butter condition^6^ but the rest of the effects were null.

###### CVD morbidity and mortality

Most of the articles reported null associations when comparing one form of dairy to another form and CVD morbidity and mortality. One article^44^ showed that substituting one form of dairy with another was associated with a lower risk of ischemic stroke, but not total stroke or hemorrhagic stroke; however, these findings were not consistent across other studies.^42,43^ Only one study assessed CVD mortality, which mainly reported null findings across different comparators.^45^

##### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on replacing or substituting one form of dairy with another by adults and older adults (Table 11).

Table 11 Conclusion statement and grade for replacing or substituting one form of dairy for another by adults and older adults and risk of cardiovascular disease

Conclusion Statement | Substituting or replacing one form of dairy (including milk, yogurt, cheese, butter and buttermilk) with another form of dairy by adults and older adults is not associated with a difference in risk of cardiovascular disease. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 10 articles (6 RCT and 4 PCS); 66 comparisonss
Consistency | Some concerns with consistency with many studies showing no effect/association.
Precision | Some concerns with precision. Sample sizes in trials were smaller. In PCS, the sample sizes were large with narrow confidence interval.
Risk of bias | Some concerns with risk of bias, mainly due to issues with exposure assessment.
Directness | Some concerns with directness primarily due to modeling approach used in the substitution analyses
Generalizability | Serious concerns with generalizability since majority of the studies were not conducted in the U.S.

###### Assessment of the evidence

The body of evidence included 10 articles that met inclusion criteria and examined the effect or association of substituting or replacing one form of dairy with another form on risk of CVD. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, because most of the studies reported null findings, publication bias may not be a major concern.

###### Consistency

There were some concerns with consistency, although most of the studies in this body of evidence showed no difference in the risk of CVD between those consuming one form of dairy compared to another. These results were noted across different intervention/exposures (i.e., milk, cheese, yogurt, butter and buttermilk), study designs (RCT, PCS), intervention durations, durations of follow-up, and outcomes.

###### Precision

There were some concerns with precision. Sample sizes in trials were smaller, although 4 of 6 articles reported power calculations. In PCS, the sample sizes were large with narrow confidence intervals. Studies also reported minimal variance, as evidenced by the relatively narrow confidence intervals.

###### Risk of bias

There were some concerns with risk of bias for most trials surrounding lack of detail regarding randomization and selection of reported results. PCS had concerns with risk of bias, primarily due to issues with confounding and exposure assessment. None of the articles accounted for race and/or ethnicity, although they accounted for all other key confounders. With regards to exposure assessment, studies combined low-fat dairy (e.g.,1%, 2% dairy products) as one group, but rarely gave additional details about the individual fat percentage of the dairy products. Studies did not have a pre-specified analysis plan, which resulted in concerns with the selection of reported results.

###### Directness

There were some concerns with directness mainly because the PCS primarily used substitution analyses. However, the PCS still addressed the research question, as they used data from a larger cohort that intended to examine relationships between diet and health. The trials directly assessed the intervention, comparator and outcomes of interest.

###### Generalizability

There were serious concerns with generalizability as none of the articles were conducted in the U.S. Race and/or ethnicity was not reported in the majority of the articles, except one which noted that the participants were predominantly White. SEP was not reported in more than half of the articles, and 3 reported medium SEP, while one reported low SEP.

#### Dairy consumption compared to food sources of carbohydrate or protein

Twelve articles assessed intake of dairy as a food source of saturated fat, compared to a food source of carbohydrate or protein, by adults and older adults.^6,9,14,16,17,22,23,26,29,31,38,41^ Ten articles were trials (7 RCT-crossover, 3 RCT-parallel)^6,9,14,16,17,22,23,26,29,31^ and 2 articles were PCS.^38,41^ Evidence comparing dairy as a source of saturated fat with carbohydrate or protein and risk of CVD in adults and older adults is summarized in Table 45. Risk of bias assessments for each article are summarized in Table 46 (RCT) and Table 47 (observational studies).

##### Description of the evidence

###### Population

Twelve articles were conducted in adults and older adults. Mean and/or median age of the participants ranged between 25 years^29^ and 58 years.^22^ Two articles exclusively enrolled female participants,^26,29^ and few studies had more female participants than male participants.^23,41^ The remaining articles were relatively balanced in terms of the sex of the participants. The sample sizes of the trials ranged between N=23^17^ and N=164.^31^ The sample sizes of the observational studies ranged between N=12,066^38^ and N= 274,754.^41^

Studies included in this body of evidence were conducted in the following countries:

○ United States, 6 articles^16,22,26,29,38,41^
○ Canada, 2 articles^6,14^
○ Australia, 1 article^17^
○ Denmark, 1 article^31^
○ Italy, 1 article^9^
○ Netherlands, 1 article^23^

Three articles exclusively enrolled participants with prehypertension and/or hypertension,^9,16,22^ while 1 article exclusively enrolled participants with hypercholesterolemia.^14^ Another article enrolled participants with hypercholesterolemia and/or hypertension.^17^ One article exclusively enrolled participants with at least two or more metabolic risk factors.^31^ One article exclusively enrolled participants with overweight and/or obesity and abdominal obesity.^6,23^ Other than these conditions, participants were generally healthy. Race and/or ethnicity was not reported in most studies, except 3 articles which noted that participants were predominantly White.^6,16,38^ SEP was not reported in most of the articles, except one which reported that the participants had low SEP.^38^

###### Intervention/exposure and comparator

The intervention or exposure was dairy, and the comparators were food sources of carbohydrate or protein. The comparators in the trials included soy and soy products (e.g., soy milk, soy yogurt, soy pudding),^14,17,26,29^ bread and jam,^9,31^ apple juice, pretzel, chocolate chip cereal bar,^16^ fruit juice and biscuits,^23^ and coconut milk, orange juice, peanuts, apple sauce^22^ The PCS comparators were eggs, legumes,^38^ and sugar-sweetened beverages.^41^

In the trials, intervention durations ranged between 4 weeks^14,26^ and 12 weeks.^31^ Adherence was reported in most trials and participants were generally adherent to the study protocols. In the PCS, the durations of follow-up ranged from ~8 years^41^ to ~22 years.^38^ FFQs were used to assess the intake of dairy and carbohydrate and proteins. While one study measured diet only at baseline, another study used a cumulative intake of diet assessed at baseline and ~6 years.

###### Outcome

Ten trials assessed the effect of dairy compared to a food source of carbohydrate and protein on fasting blood lipids and/or blood pressure^6,9,14,16,17,22,23,26,29,31^; whereas the PCS assessed CVD morbidity or mortality as the outcome.^38,41^ CVD morbidity included CHD, which is definite or probable MI or CHD death,^38,41^ while CVD mortality included total incident CHD deaths.^41^ CVD morbidity and mortality data were collected using a standardized questionnaire, medical charts, death certificates etc., which was further adjudicated.^38,41^

##### Synthesis of the evidence

###### Blood lipids and blood pressure

The intervention and comparators across these studies were too heterogeneous to synthesize the findings in a meaningful way. Most trials reported inconsistent effects between dairy compared to carbohydrate or protein comparators and blood lipids. The findings were mostly null, except one article which reported an increase in LDL-C (both butter and cheese) and decrease in triglycerides (for butter group).^6^ Findings for HDL-C were mixed with a few studies reporting null,^16,17,22,26^ 1 article reporting higher HDL-C with cheese or butter intake compared to carbohydrate,^6^ while 2 reported lower HDL-C with milk compared to soy^14^ or dairy compared to a food source of carbohydrate.^23^ Most of the studies reported null effect on blood pressure, although a few reported a tendency towards decreased blood pressure.

###### CVD morbidity and CVD mortality

Two PCS studies assessed CVD morbidity^38,41^ and 1 study assessed CVD mortality.^41^ Similar to blood lipids and blood pressure, the heterogeneity in the exposure and comparators, along with mixed findings precluded the synthesis of the evidence.

##### Conclusion statement and grade

The Committee was not able to develop a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on the relationship between dairy compared to food sources of carbohydrate and protein by adults and older adults (Table 12). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, because most studies reported null findings, publication bias may not be a major concern.

Table 12 Conclusion statement and grade for dairy consumption by adults and older adults compared carbohydrate or protein intake and risk of cardiovascular disease

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of dairy compared to food sources of carbohydrates and protein by adults and older adults and risk of cardiovascular disease because of substantial concerns with consistency in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 12 articles (10 RCT and 2 PCS); 19 comparisons
Rationale | - Serious concerns with consistency in findings across studies; - Substantial heterogeneity in intervention or exposure and comparators across studies, which precluded the synthesis of the evidence.

### Dairy sources of saturated fat compared to meat sources of saturated fat

#### Description of the evidence

Seven articles included in this review examined the relationship between substituting dairy with meat and risk of CVD.^34,38,53–57^ These articles included a nested case control study^57^ and 6 PCS.^34,38,53–56^ Evidence comparing dairy to meat and risk of CVD is summarized in Table 48. Risk of bias assessments for each article are summarized in Table 49.

##### Population

Seven articles included adults and older adults, with mean/median age ranging ~53 years to ~61 years. Most studies included similar proportions of male and female participants, although one study enrolled exclusively female participants^34^ and another one enrolled just male participants.^53^ The sample size of the included articles ranged from N=8823^57^ to N=409,885^56^ participants.

Studies were conducted in the following countries:

○ United States, 4 articles^34,38,53,54^
○ Netherlands, 1 article^57^
○ Sweden, 1 article^55^
○ European countries, 1 article^56^

Although BMI of the participants was >25 kg/m^2^ in most articles, the participants were generally healthy. Race and/or ethnicity was not reported in 3 articles.^55–57^ In the remaining articles, participants were predominantly or exclusively White.^34,38,53,54^ SEP was categorized as low in 1 article since the majority of the participants were high school graduates.^38^ Three articles had a SEP of high, since the participants were nurses and health professionals.^34,53,54^ The remaining articles were categorized as medium SEP based on education and/or income.^55–57^

##### Intervention or exposure and comparator

The intervention or exposure examined in these studies was dairy (whole-fat, high-fat, low-fat),^34,38,53–55,57^ as a category of foods, or individual dairy products, including whole milk,^53^ and cheese.^53,56^ The comparators included meat, or specifically, red meat,^34,38,53,54^ processed meat,^38,53^ red and processed meat,^55,56^ unprocessed meat,^53^ and poultry.^34,38^ All studies used a validated FFQ to assess the intake of dairy and meat. While some studies measured intake at a single time-point,^56,57^ others assessed diet every 3-4 years and used a cumulative intake as the exposure.^34,38,53–55^ All articles conducted substitution analyses, in which dairy was substituted with meat.

##### Outcomes

All included studies examined CVD morbidity and mortality, and no studies measured blood lipids or blood pressure. Most articles examined risk of CVD morbidity,^34,38,53–56^ and 1 measured risk of CVD mortality.^57^ CVD morbidity broadly encompassed CHD,^34,38,53^ ischemic heart disease,^56^ stroke^54^ and heart failure.^55^ Most of these are composite outcomes which includes both CVD morbidity and mortality.^34,38,53,56^ Studies used hospital registries, validated medical records,^34,53–56^ and death records^53^ to ascertain CVD morbidity and mortality outcomes. Many of these were adjudicated by physicians.^38,53^ The duration of follow-up ranged from ~10 years^57^ to ~30 years.^53^

#### Synthesis of the evidence

##### CVD morbidity

Most articles reported that substituting meat (i.e., red meat, processed meat, unprocessed meat) with dairy and/or dairy products (i.e., high-fat dairy, low-fat dairy, whole milk, cheese) was associated with lower risk of CVD morbidity.^34,53–56^ Specifically, when whole-fat dairy, low-fat dairy, whole milk and cheese were substituted for red meat, there was a reduction in CVD risk in almost all of the articles.^34,38,53,54^ Similarly, substituting red and processed meat with low-fat dairy or cheese was associated with lower CVD morbidity.^55,56^ When high-fat, low-fat dairy, whole milk and cheese replaced processed meat, there was a reduction in the risk of CVD morbidity in 1 article,^53^ but there was null association in another article.^38^ Substituting unprocessed meat with high-fat, low-fat dairy, whole milk and cheese was associated with reduction in CVD morbidity.^53^ Although few studies also assessed comparators such as poultry and processed meat, a separate conclusion statement was not drawn for these comparators.

##### CVD mortality

Only 1 article assessed the association between substituting processed meat with low-fat dairy.^57^ The results were trending towards reduced risk for low-fat dairy intake, when it replaced processed meat intake.

#### Conclusion statement and grade

The Committee developed 2 conclusion statements to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on meat sources of saturated fat compared with dairy sources of saturated fat in adults and older adults (Table 13).

Table 13 Conclusion statement and grade for dairy sources of saturated fat compared to meat sources of saturated fat in adults and older adults and risk of cardiovascular disease

Conclusion Statement | Substituting processed meat and red meat with dairy by adults and older adults is associated with a lower risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate. | A conclusion statement cannot be drawn about the relationship between replacing dairy with meat consumption by adults and older adults and blood lipids, blood pressure, and cardiovascular disease mortality because there is not enough evidence available.
Grade | Moderate | Grade Not Assignable
Body of Evidence | 6 PCS; 18 comparisons | 1 nested case-control
Consistency | Few concerns with consistency. Most of the studies consistently showed a lower risk of CVD morbidity when processed and red meat was replaced with dairy and dairy products. | Rationale:; - Substantial concerns with lack of evidence for blood lipids and blood pressure and CVD-mortality
Precision | Some concerns with precision. Sample sizes large with narrow confidence intervals. | Rationale:; - Substantial concerns with lack of evidence for blood lipids and blood pressure and CVD-mortality
Risk of bias | Serious concerns with risks of bias due to issues in selection of reported results, missing data, exposure assessment and confounding. | Rationale:; - Substantial concerns with lack of evidence for blood lipids and blood pressure and CVD-mortality
Directness | Some concerns with directness primarily due to modeling approach used in these substitution analyses. | Rationale:; - Substantial concerns with lack of evidence for blood lipids and blood pressure and CVD-mortality
Generalizability | Serious concerns with generalizability. Although most studies were conducted in the U.S., participants had limited diversity in race/ethnicity and socioeconomic position. | Rationale:; - Substantial concerns with lack of evidence for blood lipids and blood pressure and CVD-mortality

##### Assessment of the evidence

This body of evidence included 6 articles that met the inclusion criteria and examined the association between substituting dairy intake with meat and CVD morbidity. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, because few studies reported null findings, publication bias may not be a major concern.

##### Consistency

There were few concerns with consistency. Almost all articles reported a lower risk of CVD morbidity when processed and red meat intake was replaced with dairy and dairy products. These findings were noted with a range of exposures that included dairy, milk and cheese (both high-fat and low-fat) and irrespective of the follow-up duration (which ranged from ~13 to 30 years).

##### Precision

There were a few concerns with precision. Most of the studies in this body of evidence had more than 10,000 participants, and 2 articles had more than 100,000 participants. Studies also reported minimal variance, as evidenced by the relatively narrow confidence intervals.

##### Risk of bias

There were serious concerns with risk of bias with studies rarely having a pre-specified analysis plan, which resulted in concerns with selection of reported results. Although key confounders were consistently accounted for in most articles, race and/or ethnicity and SEP were missing in a few articles. Many studies had issues with exposure assessment, because of the lack of specificity in assessing dairy and dairy products. Several studies combined low-fat dairy as one group which included participants consuming dairy with different fat percentage (e.g.,1%, 2% dairy products) without giving additional information on the percentage of the participants that consumed each of these products. There were also concerns about missing data, primarily due to lack of information on how many participants were excluded and the rationale for their exclusion.

##### Directness

There were some concerns with directness since most of the articles were substitution studies. However, they addressed the research question, as they used data from larger cohorts that intended to examine relationships between diet and health.

##### Generalizability

There were serious concerns with generalizability. Participants from the U.S.-based studies were predominantly or exclusively White. Three articles included participants with high SEP, two with medium SEP and one with low SEP. The median age of the participants across included articles in this body of evidence was ~55 years and participants were generally healthy.

### Meat sources of saturated fat

The body of evidence examining meat sources of saturated fat consumed by adults and older adults included 39 articles.^34,38,53–89^ Sixteen articles were from RCT (11 crossover,^58,61,66–70,72,76–78^ 4 parallel,^63,65,73,79^ and 1 cluster^62^), and 23 articles were from observational studies (1 NCC^57^ and 22 PCS^34,38,53–56,59,60,64,71,74,75,80–89^).

The intervention or exposure was consumption of a meat source of saturated fat (e.g., red meat, white meat, processed meat). The evidence assessing meat sources of saturated fat consumed by adults and older adults was categorized based on 4 comparators: a similar food source with different amounts of saturated fat, a food source of monounsaturated and/or polyunsaturated fat, a food source of carbohydrate and/or protein, and a different food source of saturated fat. The Committee synthesized the evidence according to the following prioritized intervention/exposure and comparator relationships: red meat compared to plant sources of protein (e.g., beans, peas, lentils, nuts, seeds, or soy); red meat compared to fruit and vegetables; red meat compared to whole grains and cereals; red meat compared to white meat; red meat compared to fish and seafood; red meat compared to eggs; white meat compared to plant-based foods (e.g., plant sources of protein, fruit and vegetables, grains and cereals); white meat versus fish and seafood; meat compared to plant-based foods in trials; meat with different amounts of saturated fat; and processed meat compared to unprocessed meat. Some articles contributed data to more than one category. In addition, some articles were not included in evidence synthesis (Appendix 4).

#### Red meat compared to plant sources of protein

##### Description of the evidence

Thirteen articles compared red meat to plant sources of protein (e.g., beans, peas, lentils, nuts, seeds, or soy) in adults and older adults: 1 crossover RCT^58^; 1 NCC^57^; 11 PCS^34,38,53–55,74,80,81,83,87,88^. Evidence from red meat compared to plant sources of protein in adults and older adults and risk of cardiovascular disease is summarized in Table 50. Risk of bias assessments for each article are summarized in Table 51 (RCT) and Table 52 (observational).

###### Population

Mean baseline age ranged from 36 to 62 years; 3 articles^57,80,83^ were conducted in participants with a mean age ≥60 years. Three articles^34,80,81^ enrolled only females, 1 article^53^ enrolled only males, and 1 article^83^ was 88% male; all other articles had relatively even distribution of male and female enrollment. The trial^58^ had an analytic sample size of N=113. Observational studies had sample sizes ranging from N=456 to N=148,506; 2 studies^74,88^ had analytic sample sizes less than 10,000 participants.

Articles included in this body of evidence were conducted in the following countries:

- United States: 9 articles^34,38,53,54,58,74,80,83,87^
- France: 1 article^81^
- Sweden: 1 article^55^
- The Netherlands: 1 article^57^
- Multiple countries (Finland, UK, New Zealand, Australia): 1 article^88^

Eight articles were conducted in predominately White/Caucasian samples.^34,38,53,54,74,80,83,88^ Two articles had more diverse racial and/or ethnic representation: 55% White, 12% African American, 20% Asian, 13% Other^58^; 69% non-Hispanic White, 24% non-Hispanic Black, 4.5% Hispanic, 2% Chinese, <1% Other.^87^ Three articles did not report data on race and/or ethnicity.^55,57,81^

Three articles were conducted in primarily well-educated samples.^34,53,54^ Eight articles^38,55,57,74,80,81,83,87^ were diverse in terms of participant education and/or income levels, and 2 articles^58,88^ did not report data on socioeconomic position.

One article exclusively enrolled participants with overweight or obesity and prediabetes.^88^ All other articles enrolled participants who were generally healthy and without chronic disease.

###### Intervention/exposure and comparator

The intervention or exposure of interest was red meat, which included unprocessed red meat, processed red meat, or total red meat (unprocessed and processed red meat combined). Six articles^38,53,58,74,83,87^ examined unprocessed red meat consumption, 8 articles^38,53,57,74,81,83,87,88^ examined processed red meat consumption, and 6 articles^34,53–55,80,83^ examined consumption of total red meat. Zhu et al^88^ included luncheon meat made from poultry in their measure of “processed meat”.

Comparators of interest included plant sources of protein (e.g., beans, peas, lentils, nuts, seeds, or soy):

- Nuts: 9 articles^34,38,53,54,57,80,83,87,88^
- Nuts and legumes (peas, pea soup, soya, nuts): 1 article^55^
- Legumes: 6 articles^38,53,74,83,87,88^
  ○ “Pulses, beans, peas, lentils, soy foods”^88^
  ○ “Beans, lentils, soybeans, string beans, and tofu”^74^
  ○ “Soy products, beans, and peas”^80^
  ○ “Dry beans, peas, soy, and tofu”^54^
  ○ Did not provide details on legumes^38,87^
- Beans/legumes: 2 articles^53,83^
  ○ “Beans or lentils (baked, dried or soup); peas or lima beans (fresh, frozen, canned) or soup”^53^
  ○ Did not provide details on beans/legumes^83^
- Beans (including lentils, baked or dry): 1 article^34^
- Non-meat proteins (legumes, nuts, grains, isoflavone-free soy products): 1 article^58^
- Soy (“tofu, soy burger, soybeans, miso or other soy protein”): 1 article^53^
- Plant-based proteins (“nuts, beans/legumes, and soy foods”): 1 article^53^
- Pulses: 2 articles^57,81^ (both articles did not report details on pulses)

The crossover RCT compared lean red meat (11% energy from lean cuts of grain-finished beef and 1% energy from lean cuts of pork) to non-meat sources of protein (legumes, nuts, grains, isoflavone-free soy products); each condition lasted 4 weeks separated by a 2- to 7-week washout period.^58^

Among observational studies, most studies measured red meat consumption with a validated FFQ; 1 article^88^ used a 4-day diet record. Five articles^57,74,80,83,87^ measured red meat consumption at baseline only, and 7 articles^34,38,53–55,81,88^ assessed diet over multiple time points. Most observational studies modeled the substitution of red meat with plant sources of protein as a continuous measure (e.g., 1 serving per day substitution).

###### Outcomes

Two articles measured fasting blood lipids at multiple time points.^58,88^ The trial^58^ examined LDL-C, HDL-C, and triglycerides at baseline and after the 4-week intervention, and the PCS^88^ examined mean change in triglycerides per year over 3 years. The trial^58^ measured blood pressure and Thao et al^81^ examined incidence of self-reported hypertension based on date of diagnosis and use of medication over an 18-year follow-up period.

Eight articles^34,38,53–55,74,83,87^ examined CVD morbidity (stroke^54^; heart failure^55^; fatal and non-fatal CHD or CVD^34,38,53,83,87^), which was often collected from medical records and patient registries (and confirmed in some studies); Razavi et al^74^ examined left ventricular diastolic dysfunction measured from echocardiography. Average follow-up duration for CVD morbidity ranged from 4 to 30 years.

Two articles assessed CVD mortality using death certificates, medical records, autopsy reports, or linkage to national registries; average follow-up duration for CVD mortality ranged from 10 to 18 years.^57,80^

##### Synthesis of the evidence

Synthesis of the evidence comparing red meat to plant sources of protein focused on CVD morbidity due to the lack of data on blood lipids, blood pressure, hypertension, and CVD mortality. The conclusion statement is based solely on substitution analyses from prospective cohort studies. No studies exclusively enrolled an older adult population, though many included older adults. As a result, there is not a separate conclusion statement for older adults, and the conclusion statement drawn applies to all adults, including older adults.

Most analyses showed a significant, beneficial association between substituting plant sources of protein for red meat and risk of CVD morbidity. This relationship was consistent across red meat types: unprocessed red meat, processed red meat, and total red meat (unprocessed and processed red meat combined) regardless of whether they were examined separately or together. Consequently, all red meat types were synthesized together. The relationship was also consistent across different types of plant sources of protein, including beans, peas, lentils, nuts, seeds, and soy, regardless of how the original studies grouped them.

Roughly one third of the analyses found non-significant associations, though some also trended toward a beneficial association between substituting red meat with plant sources of protein and risk of CVD morbidity. No studies found a detrimental association between substituting red meat with plant sources of protein and risk of CVD morbidity.

##### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on red meat compared to plant sources of protein by adults and older adults (Table 14).

Table 14 Conclusion statement and grade for red meat compared to plant sources of protein in adults and older adults and risk of cardiovascular disease

Conclusion Statement | Substituting processed or unprocessed red meat with plant sources of protein (such as beans, peas, lentils, nuts, seeds, or soy) by adults and older adults is associated with lower risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 8 articles: all PCS (33 comparisons; all substitution analyses)
Consistency | Few concerns with consistency. Almost all analyses showed a beneficial relationship.
Precision | Few concerns with precision. Sample sizes were large, and confidence intervals were narrow.
Risk of bias | Some concerns with risk of bias, particularly due to unadjusted confounding, missing data, and not having preregistered data analysis plans.
Directness | Some concerns with directness, primarily due to the modeling approach used for these substitution analyses and the lack of trial data.
Generalizability | Substantial concerns with generalizability. Although most studies were conducted in the U.S., there was limited diversity in race and/or ethnicity and socioeconomic position.

###### Assessment of the evidence

The body of evidence underlying the conclusion statement included 33 comparisons (all substitution analyses) from 8 PCS. The strength of the evidence was graded based on an assessment of five grading elements, as described below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, the body of evidence included studies with null findings, so there was less concern of publication bias.

###### Consistency

Most studies showed a significant, beneficial association between substituting red meat with plant sources of protein and risk of CVD morbidity. These findings were consistent across the body of evidence, both within and across the different types of red meat and within and across the different plant sources of protein. For the small number of non-significant results, roughly half trended in the same direction as the significant findings.

###### Precision

There were few concerns with precision. Sample sizes were large across the observational evidence, and confidence intervals were narrow.

###### Risk of bias

There were some concerns with risk of bias, primarily in the areas of unadjusted confounding, inadequate information on or adjustment for missing data, and not having a preregistered data analysis plan. This affected roughly half of the cohort studies, while the other half had lower risk of bias, in general.

###### Directness

The analyses were designed to answer the question of interest. Therefore, the primary concern with directness was the reliance of substitution analyses and the lack of other observational or trial data on this relationship.

###### Generalizability

Most studies in this body of evidence were conducted in the U.S. but considered predominantly White/Caucasian populations, limiting generalizability to other racial and/or ethnic groups. There was more diversity in socioeconomic position across studies, and all but one study enrolled generally healthy populations without chronic disease.

#### Red meat compared to fruit and vegetables

##### Description of the evidence

Six articles compared red meat to fruit and vegetables in adults and older adults: 1 parallel RCT^73^ and 5 PCS^55,74,81,83,85^. Evidence from red meat compared to fruit and vegetables in adults and older adults and risk of cardiovascular disease is summarized in Table 53. Risk of bias assessments for each article are summarized in Table 54 (RCT) and Table 55 (observational).

###### Population

Mean baseline age ranged from 36 to 61 years; 1 article^83^ was conducted in participants with a mean age ≥60 years. One article^81^ enrolled only females and 1 article^83^ was 88% male; all other articles had relatively even distribution of male and female enrollment. The trial had an analytic sample size of N=73.^73^ Observational studies had sample sizes ranging from N=456 to N=148,506; one study^74^ had analytic sample sizes less than 10,000 participants.

Articles included in this body of evidence were conducted in the following countries:

- United States: 3 articles^73,74,83^
- Denmark: 1 article^85^
- France: 1 article^81^
- Sweden: 1 article^55^

Two PCS were conducted in predominately White/Caucasian samples.^74,83^ The trial had more diverse racial and/or ethnic representation: 53% African American, 45% White/Caucasian, 2% Hispanic.^73^ Three articles did not report data on race and/or ethnicity.^55,81,85^

Four articles were diverse in terms of participant education and/or income levels.^55,74,81,83^ Two articles did not report data on socioeconomic position.^73,85^

The trial^88^ had inclusion criteria for BMI 25-40 kg/m^2^. The articles from observational studies enrolled participants who were generally healthy and without chronic disease.

###### Intervention/exposure and comparator

The intervention or exposure of interest was red meat, which included unprocessed red meat, processed red meat, or total red meat (unprocessed and processed red meat combined). Four articles^73,74,83,85^ examined unprocessed red meat consumption, 4 articles^74,81,83,85^ examined processed red meat consumption, and 3 articles^55,83,85^ examined consumption of total red meat.

Comparators of interest included fruit and vegetables:

- Fruit (“orange, apple, banana, berries, other fruits”): 1 article^55^
- Potatoes (“including boiled, baked, roasted, fried and mashed potatoes”): 1 article^85^
- Mushrooms: 1 article from an RCT^73^
- Vegetables: 5 articles^55,74,81,83,85^
  ○ “Carrot, beetroot, lettuce, cabbage, cauliflower, broccoli, tomato, pepper, spinach, onion, garlic, other vegetables but not including potatoes”^55^
  ○ “Leafy and root vegetables (excluding potatoes and pulses)”^81^
  ○ “Fruiting vegetables (cucumber, aubergine, green pepper, red pepper, tomato, zucchini, avocado, green beans, green peas, maize), leafy vegetables (spinach, lettuce), root vegetables (carrot, celeriac, ginger), cabbage (cauliflower, broccoli, red cabbage, white cabbage, kale, Brussels sprouts), mushrooms (champignon, chanterelle), onion (onion, garlic) and stalk vegetables/sprouts (leek, bean sprouts, chives, asparagus, bamboo shoots, rhubarb); also included a few mixed dishes such as salad and vegetable patties, and vegetable content from standard recipes such as stew contributed small amounts”^85^
  ○ Fresh (“tomatoes, broccoli, beets, corn, peas, mixed vegetables, spinach, kale, peppers, yams, zucchini, carrots, celery, and lettuce”)^74^
  ○ Did not provide details on vegetables^83^

The RCT^73^ was a 12-month intervention (6-month weight loss and 6-month weight maintenance) in which one group consumed ≥90% lean ground beef at 3 meals each week compared to a group that substituted white button mushrooms (8 oz) for red meat at 3 meals each week by incorporating it in sauteed vegetables, “burgers”, and other normally meat-containing dishes. All participants were prescribed a 500 kilocalorie per day energy-deficit diet in the first 6 months. The group consuming mushrooms received dietary instruction on preparing and using mushroom substitutes for meat whereas the group consuming beef received dietary instruction without the recommendation of mushroom substitution.

Among observational studies, all studies measured red meat consumption with a validated FFQ. Three articles^74,83,85^ measured red meat consumption at baseline only, and 2 articles^55,81^ assessed diet over multiple time points. Most observational studies modeled the substitution of red meat with fruit or vegetables as a continuous measure (e.g., 1 serving per day substitution).

###### Outcomes

The trial examined change in LDL-C (from fasting blood samples) and blood pressure during the 6-month weight loss and 6-month weight maintenance periods^73^; there was no between-group data on HDL-C or triglycerides. Thao et al^81^ examined incidence of self-reported hypertension based on date of diagnosis and use of medication over an 18-year follow-up period.

Four articles^55,74,83,85^ examined CVD morbidity (fatal and non-fatal MI or CVD^74,83^; heart failure^55^) collected from national registries and medical records; Razavi et al^74^ examined left ventricular diastolic dysfunction measured from echocardiography. Average follow-up duration ranged from 4 to 22 years.

No articles examined CVD mortality.

##### Synthesis of the evidence

Synthesis of the evidence comparing red meat to fruit and vegetables focused on CVD morbidity due to inadequate data on LDL-C and blood pressure and no data on HDL cholesterol, triglycerides, or CVD mortality. The conclusion statement is based solely on substitution analyses from prospective cohort studies. No studies exclusively enrolled an older adult population, though many included older adults. As a result, there is not a separate conclusion statement for older adults, and the conclusion statement drawn applies to all adults, including older adults.

Most analyses showed a significant, beneficial association between substituting vegetables for red meat and risk of CVD morbidity. This relationship was consistent across red meat types: unprocessed red meat, processed red meat, and total red meat (unprocessed and processed red meat combined) regardless of whether they were examined separately or together. Consequently, all red meat types were synthesized together.

The majority of analyses specifically targeted vegetables and showed consistent relationships with all red meat types. One study found a beneficial relationship for substituting total red meat (unprocessed and processed red meat combined) with vegetables, but when red meat types were examined separately, different associations were found for male and female participants. Substituting processed red meat with vegetables was associated with lower CVD morbidity for men but not women. Conversely, substituting unprocessed red meat with vegetables was associated with lower CVD morbidity for women but not men.^85^

The same article that stratified vegetable analyses by sex did the same for potatoes, specifically, and again showed mixed findings. Substituting potatoes for total red meat was related to lower CVD morbidity risk for women and trended in that direction for men. When examining the red meat types separately, replacing processed red meat with potatoes was significantly related to lower CVD morbidity for men but not women; the inverse was true when substituting unprocessed meat with potatoes, which was significant for women but not men.^85^ The single analysis on fruit showed a beneficial association between substituting total red meat with fruit.^55^ There were inadequate data on potatoes or fruit to include them in the conclusion.

Overall, findings from these substitution analyses indicate a beneficial relationship between substituting red meat with vegetables on CVD morbidity. No studies found a detrimental association between substituting vegetables for red meat and risk of CVD morbidity. One article stratified by sex and suggested there may be between-sex differences in this relationship, but specific conclusions could not be drawn on those subgroups since no other analyses provided this data.

##### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on red meat compared to vegetables by adults and older adults (Table 15).

Table 15 Conclusion statement and grade for red meat compared to vegetables in adults and older adults and risk of cardiovascular disease

Conclusion Statement | Substituting processed or unprocessed red meat with vegetables by adults and older adults is associated with lower risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 4 articles: all PCS (12 comparisons, all substitution analyses)
Consistency | Few concerns with consistency. Almost all analyses showed a beneficial relationship.
Precision | Few concerns with precision. Sample sizes were large, and confidence intervals were narrow.
Risk of bias | Some concerns with risk of bias, particularly due to unadjusted confounding, exposure measurement, missing data, and not having preregistered data analysis plans
Directness | Some concerns with directness, primarily due to the modeling approach used for these substitution analyses and the lack of trial data
Generalizability | Substantial concerns with generalizability due to limited diversity in race and/or ethnicity and socioeconomic position. Half of the studies were conducted in the U.S.

###### Assessment of the evidence

The body of evidence underlying the conclusion statement included 12 comparisons (all substitution analyses) from 4 PCS. The strength of the evidence was graded based on an assessment of five grading elements, as described below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, the body of evidence included studies with null findings, so there was less concern of publication bias.

###### Consistency

Findings were consistent across the body of evidence for vegetables, with most studies finding a beneficial association with CVD morbidity. The evidence base was too small to determine if this relationship persisted when looking at the different types of red meat, individually, but it was consistent when looking at red meat, overall.

###### Precision

There were few concerns with precision beyond the small number of studies available to answer this question. Sample sizes were large across the observational evidence, and confidence intervals were narrow.

###### Risk of bias

There were some concerns with risk of bias, primarily in the areas of unadjusted confounding, exposure measurement (e.g., measuring only once), inadequate information on or adjustment for missing data, and not having a preregistered data analysis plan.

###### Directness

The analyses were designed to answer the question of interest. Therefore, the primary concern with directness was the reliance of substitution analyses and the lack of other observational or trial data on this relationship.

###### Generalizability

Roughly half of the studies in this body of evidence were conducted in the U.S. The majority of studies did not report data on race and/or ethnicity, limiting the ability to determine generalizability across racial and/or ethnic groups. Socioeconomic position was more commonly reported, and samples in this body of evidence showed substantial diversity. All studies examined generally healthy populations without chronic disease.

#### Red meat compared to whole grains and cereals

##### Description of the evidence

Six articles compared red meat to whole grains and cereals in adults and older adults: all PCS.^53,55,83,84,87,88^ Evidence from red meat compared to whole grains and cereals in adults and older adults and risk of cardiovascular disease is summarized in Table 56. Risk of bias assessments for each article are summarized in Table 57.

###### Population

Mean baseline age ranged from 53 to 61 years; one article^83^ was conducted in participants with a mean age ≥60 years. One article^53^ enrolled only males and 1 article^83^ was 88% male; all other articles had relatively even distribution of male and female enrollment. Observational studies had sample sizes ranging from N=668 to N=180,642; one study^88^ had an analytic sample size less than 10,000 participants.

Articles included in this body of evidence were conducted in the following countries:

- United States: 3 articles^53,83,87^
- Sweden: 1 article^55^
- UK: 1 article^84^
- Multiple countries (Finland, UK, New Zealand, Australia): 1 article^88^

Four articles were conducted in predominately White/Caucasian samples.^53,83,84,88^ One article^87^ had more diverse racial and/or ethnic representation: 69% non-Hispanic White, 24% non-Hispanic Black, 4.5% Hispanic, 2% Chinese, <1% Other. One article did not report data on race and/or ethnicity.^55^

One article was conducted in a primarily well-educated sample.^53^ Four articles were diverse in terms of participant education and/or income levels.^55,83,84,87^ One article did not report data on socioeconomic position.^88^

One article enrolled participants with overweight or obesity and prediabetes.^88^ All other articles enrolled participants who were generally healthy and without chronic disease.

###### Intervention/exposure and comparator

The intervention or exposure of interest was red meat, which included unprocessed red meat, processed red meat, or total red meat (unprocessed and processed red meat combined). Four articles^53,83,84,87^ examined unprocessed red meat consumption, 4 articles^53,83,87,88^ examined processed red meat consumption, and 3 articles^53,55,83^ examined consumption of total red meat. Zhu et al^88^ included luncheon meat made from poultry in their measure of “processed meat”.

Comparators of interest included whole grains and cereals:

- Whole grains: 4 articles^53,55,83,87^
- Cereal: 1 article^84^
- “Grains” (which included breads, cereals, pasta, and potatoes): 1 article^88^

Most studies measured red meat consumption with a validated FFQ; 1 article^88^ used a 4-day diet record. Three articles^83,84,87^ measured red meat consumption at baseline only and 3 articles^53,55,88^ assessed diet over multiple time points. All studies modeled the substitution of red meat with whole grains or cereals as a continuous measure (e.g., 1 serving per day substitution).

###### Outcomes

One article collected fasting blood samples and examined mean change in triglycerides per year over 3 years.^88^ No articles provided data on LDL-C, HDL-C, or blood pressure.

Four articles examined CVD morbidity (heart failure^55^; fatal and non-fatal CHD or CVD^53,83,87^), which was often collected from medical records and patient registries. Average follow-up duration for CVD morbidity ranged from 4 to 30 years.

One article assessed mortality from CVD, CHD, and stroke over an 8-year follow-up using death certificates.^84^

##### Synthesis of the evidence

Synthesis of the evidence comparing red meat to whole grains and cereals focused on CVD morbidity due inadequate data on CVD mortality and triglyceride levels and no data on LDL-C, HDL-C, or blood pressure. The conclusion statement is therefore based solely on substitution analyses from prospective cohort studies. No studies exclusively enrolled an older adult population, though many included older adults. As a result, there is not a separate conclusion statement for older adults, and the conclusion statement drawn applies to all adults, including older adults.

All but one analysis showed a beneficial association between substituting whole grains for red meat and risk of CVD morbidity, and the single non-significant finding trended in the same direction. No studies found a detrimental association between substituting whole grains for red meat and risk of CVD morbidity. This relationship was seen consistently across red meat types: unprocessed red meat, processed red meat, and total red meat (unprocessed and processed red meat combined), though the evidence base was very small when examining red meat types separately. Consequently, all red meat types were synthesized together. Analyses of CVD morbidity exclusively included whole grains and did not include the broader “grains” exposure nor the cereal exposure, which were examined for other outcomes only.

##### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on red meat compared to whole grains by adults and older adults (Table 16).

Table 16 Conclusion statement and grade for red meat compared to whole grains in adults and older adults and risk of cardiovascular disease

Conclusion Statement | Substituting processed or unprocessed red meat with whole grains by adults and older adults is associated with lower risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 4 articles: all PCS (9 comparisons, all substitution analyses)
Consistency | Few concerns with consistency. All studies showed a beneficial relationship.
Precision | Some concerns with precision. The number of studies was small, but sample sizes were large, and confidence intervals were narrow.
Risk of bias | Some concerns with risk of bias, particularly due to unadjusted confounding, exposure measurement, missing data, and not having preregistered data analysis plans
Directness | Some concerns with directness, primarily due to the modeling approach used for these substitution analyses and the lack of trial data
Generalizability | Some concerns with generalizability. Although most studies were conducted in the U.S., there was limited diversity in race and/or ethnicity. Socioeconomic position was more diverse.

###### Assessment of the evidence

The body of evidence underlying the conclusion statement included 9 comparisons (all substitution analyses) from 4 PCS. The strength of the evidence was graded based on an assessment of five grading elements, as described below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, the body of evidence included studies with null findings, so there was less concern of publication bias.

###### Consistency

Findings were consistent across the body of evidence for whole grains, with most studies finding a beneficial association with CVD morbidity. The evidence base was too small to determine if this relationship persisted when looking at the different types of red meat, individually, but it was consistent when looking at red meat, overall.

###### Precision

There were few concerns with precision beyond the small number of studies available to answer this question. Sample sizes were large across the observational evidence, and confidence intervals were narrow.

###### Risk of bias

There were substantial concerns with risk of bias, primarily in the areas of unadjusted confounding, exposure measurement (e.g., measuring only once), inadequate information on or adjustment for missing data, and not having a preregistered data analysis plan.

###### Directness

The analyses were designed to answer the question of interest. Therefore, the primary concern with directness was the reliance of substitution analyses and the lack of other observational or trial data on this relationship.

###### Generalizability

Most studies in this body of evidence were conducted in the U.S. but considered predominantly White/Caucasian populations, limiting generalizability to other racial and/or ethnic groups. There was more diversity in socioeconomic position across studies, and all but one enrolled generally healthy populations without chronic disease.

#### Red meat compared to white meat

##### Description of the evidence

Twenty-two articles compared red meat to white meat in adults and older adults: 6 RCT (1 parallel,^79^ 5 crossover^58,68,69,72,78^); 1 NCC57; 15 PCS^34,38,53,54,56,59,60,71,80,81,83,84,86–88^. Evidence from red meat compared to white meat in adults and older adults and risk of cardiovascular disease is summarized in Table 58. Risk of bias assessments for each article are summarized in Table 59 (RCT) and Table 60 (observational).

###### Population

Mean baseline age ranged from 36 to 62 years; 3 articles^57,80,83^ were conducted in participants with a mean age ≥60 years. Three articles^34,80,81^ enrolled only females, 1 article^53^ enrolled only males, and 2 articles^60,83^ were >70% male; all other articles had relatively even distribution of male and female enrollment. Analytic sample sizes of the study groups among the trials ranged from N=38 to N=113. Observational studies had sample sizes ranging from N=456 to N=409,885; two studies^60,88^ had analytic sample sizes less than 10,000 participants.

Articles included in this body of evidence were conducted in the following countries:

- United States: 11 articles^34,38,53,54,58,59,72,79,80,83,87^
- Spain: 3 articles^68,69,78^
- Denmark: 2 articles^71,86^
- UK: 2 articles^60,84^
- France: 1 article^81^
- The Netherlands: 1 article^57^
- Multiple European countries: 1 article^56^
- Multiple countries (Finland, UK, New Zealand, Australia): 1 article^88^

Eleven articles were conducted in predominately White/Caucasian samples.^34,38,53,54,59,60,72,80,83,84,88^ Two articles had more diverse racial and/or ethnic representation: 55% White, 12% African American, 20% Asian, 13% Other^58^; 69% non-Hispanic White, 24% non-Hispanic Black, 4.5% Hispanic, 2% Chinese, <1% Other^87^. Nine articles did not report data on race and/or ethnicity.^56,57,68,69,71,78,79,81,86^

Five articles were conducted in primarily well-educated samples.^34,53,54,59,71^ Eleven articles^38,56,57,60,78,80,81,83,84,86,87^ were diverse in terms of participant education and/or income levels and 6 articles^58,68,69,72,79,88^ did not report data on socioeconomic position.

One trial^72^ had inclusion criteria for BMI 25-37 kg/m^2^ and another trial^79^ recruited men with hypercholesterolemia. One PCS enrolled participants with overweight or obesity and prediabetes.^88^ All other articles enrolled participants who were generally healthy and without chronic disease.

###### Intervention/exposure and comparator

The intervention or exposure of interest was red meat, which included unprocessed red meat, processed red meat, or total red meat (unprocessed and processed red meat combined). Fourteen articles^38,53,58,60,68,69,71,72,78,79,83,84,86,87^ (including 6 trials^58,68,69,72,78,79^) examined unprocessed red meat consumption, 9 articles^38,53,57,71,81,83,86–88^ examined processed red meat consumption, and 9 articles^34,53,54,56,59,71,80,83,86^ examined consumption of total red meat. Zhu et al^88^ included luncheon meat made from poultry in their measure of “processed meat”.

The comparator of interest was white meat:

- White meat/poultry: 11 articles^34,53,54,56,57,59,71,80,83,86,88^
  ○ Unprocessed white meat: 9 articles^53,56,57,59,71,80,83,86,88^
    ▪ “Chicken/turkey sandwich or frozen dinner; other chicken or turkey, with skin -including ground; other chicken or turkey, without skin”^53^
    ▪ “White meat, excluding processed poultry”^56^
    ▪ Chicken and/or turkey (with and/or without skin)^57,59,71,83,86^
    ▪ Chicken, turkey, and other poultry^80,88^
  ○ Processed white meat: 0 articles
  ○ Total white meat (unprocessed and processed white meat combined): 2 articles^34,54^
    ▪ “Chicken with and without skin, chicken sandwich, and chicken/turkey hot dog”^34,54^
- Ratio of white to red meat as one of the 9 components of AHEI: 1 article^60^
- Did not provide details on white meat/poultry: 4 articles^38,81,84,87^

All trials compared unprocessed red meat to unprocessed white meat. The details are as follows:

- Bergeron et al^58^ compared lean red meat (11% energy from lean cuts of grain-finished beef and 1% energy from lean cuts of pork) to lean white meat (8% energy from chicken and 4% energy from turkey); the intervention duration was 4 weeks separated by a 2- to 7-week washout period.
- Mateo-Gallego et al^68^ compared lamb to chicken (both groups consumed 125 grams of roasted, grilled, or stewed meat 3 times per week; the intervention duration was 5 weeks with no washout period.
- Mesana Graffe et al^69^ compared lamb to chicken (both groups consumed 150 grams of roasted, grilled, or stewed meat 3 times per week; the intervention duration was 8 weeks separated by a 5-week washout period.
- O’Connor et al^72^ conducted a 16-week trial in which participants consumed a Mediterranean Pattern diet that differed predominantly in the amounts of red meat and poultry provided. One group consumed approximately 476 grams per week of lean, unprocessed beef or pork and 112 grams per week of lean, unprocessed poultry; another group consumed 196 grams per week of lean, unprocessed beef or pork and 420 grams per week of lean, unprocessed poultry. The intervention duration was 5 weeks separated by a ≥4-week washout, in which participants consumed a self-selected and unrestricted eating pattern.
- Santaliestra-Pasías et al^78^ compared lean beef (200 grams with bones, 3 days per week) to chicken (150 grams boneless, 3 days per week); the intervention duration was 8 weeks separated by a 5-week washout.
- Scott et al^79^ compared lean beef (8% fat) to chicken breast; both groups consumed 85 grams each day for 5 weeks.

Most observational studies measured red meat consumption with a validated FFQ; 1 article^88^ used a 4-day diet record. Eight articles^56,57,71,80,83,84,86,87^ measured red meat consumption at baseline only and 8 articles^34,38,53,54,59,81,88^ assessed diet over multiple time points. Most observational studies modeled the substitution of red meat with white meat as a continuous measure (e.g., 1 serving per day substitution or 150 grams per week substitution).

###### Outcomes

All trials measured fasting blood lipids (LDL-C, HDL-C, and triglycerides)^58,68,69,72,78,79^; three trials^58,72,78^ also measured blood pressure. Intervention duration ranged from 4 to 8 weeks. Two PCS collected fasting blood samples.^60,88^ Zhu et al^88^ examined mean change in triglycerides per year over 3 years and Bouillon et al^60^ examined change in LDL-C over an 11-year follow-up. Two PCS examined self-reported hypertension (based on annual questionnaires^59^ or date of diagnosis and use of medication^81^) over an 18- to 26-year follow-up.

Eight articles examined CVD morbidity (stroke^54^; fatal or non-fatal ischemic heart disease^56^; fatal and non-fatal MI, CHD, or CVD^34,38,53,83,86,87^) collected from national registries and medical records. Average follow-up duration for CVD morbidity ranged from 4 to 30 years.

Four articles examined CVD mortality using death certificates, medical records, autopsy reports, or linkage to national registries; average follow-up duration for CVD mortality ranged from 8 to 18 years.^57,71,80,84^

##### Synthesis of the evidence

Synthesis of the observational studies comparing red meat to white meat focused on CVD morbidity due inadequate data on CVD mortality. The conclusion statement for observational evidence is based solely on substitution analyses. Synthesis of the trials focused on blood lipids (LDL-C, HDL-C, triglycerides) and blood pressure. No studies exclusively enrolled an older adult population, though many included older adults. As a result, there is not a separate conclusion statement for older adults, and the conclusion statements drawn apply to all adults, including older adults.

Almost all analyses examining this relationship found substituting red meat with white meat was not associated with risk of CVD morbidity. Two analyses showed a beneficial association between substituting total red meat (unprocessed and processed combined) with white meat.^34,54^ When looking at the red meat types individually, no analyses showed a significant relationship when substituting unprocessed red meat with white meat while 2 showed a trending but non-significant relationship when looking at processed red meat.^53,87^

The trials focused primarily on lean red meat compared to lean white meat consumption and found few differences in blood lipid or blood pressure levels across the duration of the trial, which ranged from 4 to 8 weeks. Differences in findings did not vary by the specific type or amount of meat prescribed, both of which were reasonably consistent across trials. The small number of significant findings indicated a beneficial impact of lean red meat compared to lean white meat. Only half of the trials examined blood pressure, and none found significant differences between meat types for blood pressure. All trials measured blood lipids, though none found significant differences for more than 1 blood lipid value. One study found LDL-C was lower in the lean red meat condition, but HDL-C and triglycerides did not vary.^72^ Another found HDL-C was higher in the lean red meat condition, but LDL-C and triglycerides did not vary.^68^ A third found triglyceride levels were lower in the lean red meat condition, but neither LDL-C nor HDL-C varied.^69^

The quality of trial design varied considerably across this small body of evidence, and multiple studies appeared designed to demonstrate equivalence between red and white meat. The primary areas of concern included randomization methods, the specificity of the meat examined (which limits generalizability to the broader U.S. diet), the inclusion of run-in periods with higher prescribed saturated fat intake than the experimental periods, and funding source. Overall, limitations in study design, variability in the study foods included, and inconsistency in findings prevented a conclusion statement from being drawn for the trial data.

##### Conclusion statements and grades

The Committee developed 2 conclusion statements to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on red meat compared to white meat in adults and older adults (Table 17).

Table 17 Conclusion statements and grades for red meat compared to white meat in adults and older adults and risk of cardiovascular disease

Conclusion Statement | Substituting processed or unprocessed red meat with white meat by adults and older adults is not associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate. | Replacing consumption of lean, unprocessed red meat with lean, unprocessed white meat by adults and older adults may not affect blood lipids or blood pressure. This conclusion statement is based on evidence graded as limited.
Grade | Moderate | Limited
Body of Evidence | 8 articles: all PCS (16 comparisons, all substitution analyses) | 6 articles: all RCT
Consistency | Few concerns with consistency. Almost all analyses showed no relationship. | Some concerns with consistency. Most analyses showed no relationship.
Precision | Few concerns with precision. Sample sizes were large, and confidence intervals were narrow. | Substantial concerns with precision, particularly due to small sample sizes, study design concerns
Risk of bias | Substantial concerns with risk of bias, particularly due to unadjusted confounding, exposure measurement, missing data, and not having preregistered data analysis plans | Substantial concerns with risk of bias, particularly due to deviations from intended interventions and selection of the reported result
Directness | Some concerns with directness, primarily due to the modeling approach used for these substitution analyses and the lack of trial data | Some concerns with directness due to study design and specificity of food sources
Generalizability | Some concerns with generalizability due to limited diversity in race and/or ethnicity. Socioeconomic position was more diverse. Half of the studies were conducted in the U.S. | Substantial concerns with generalizability due to limited diversity in race and/or ethnicity and socioeconomic position. Half of the studies were conducted in the U.S.

###### Assessment of the evidence: Substituting processed or unprocessed red meat with white meat

The body of evidence underlying the conclusion statement for substituting processed or unprocessed red meat with white meat and CVD morbidity included 16 comparisons (all substitution analyses) from 8 PCS. The strength of the evidence was graded based on an assessment of five grading elements, as described below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias.

###### Consistency

Findings on substituting red meat with white meat were consistent across the body of evidence, with almost all showing no relationship with CVD morbidity. This was true both within and across the different types of red meat.

###### Precision

There were few concerns with precision. Sample sizes were large across the observational evidence, and confidence intervals were narrow.

###### Risk of bias

There were substantial concerns with risk of bias, primarily in the areas of unadjusted confounding, exposure measurement (e.g., measuring only once), inadequate information on or adjustment for missing data, and not having a preregistered data analysis plan.

###### Directness

The analyses were designed to answer the question of interest. Therefore, the primary concern with directness was the reliance of substitution analyses and the lack of other observational or trial data on this relationship.

###### Generalizability

Most studies in this body of evidence considered predominantly White/Caucasian populations, limiting generalizability to other racial and/or ethnic groups. There was more diversity in socioeconomic position across studies, and all but one enrolled generally healthy populations without chronic disease. Roughly half of the studies were conducted in the U.S.

###### Assessment of the evidence: Replacing lean, unprocessed red meat with lean, unprocessed white meat

The body of evidence underlying the conclusion statement for replacing consumption of lean, unprocessed red meat with lean, unprocessed white meat and blood lipids and blood pressure included 6 RCT. The strength of the evidence was graded based on an assessment of five grading elements, as described below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, the body of evidence included both small and large studies, including small studies with null findings, so there was less concern of publication bias.

###### Consistency

There were some concerns with consistency. Most analyses showed no relationship with blood lipids or blood pressure; a small number showed beneficial effect of lean unprocessed red meat on blood lipids.

###### Precision

There were substantial concerns with precision. Sample sizes were small across the trial evidence.

###### Risk of bias

There were substantial concerns with risk of bias, particularly due to deviations from intended interventions, carryover effects, and selection of the reported result.

###### Directness

The analyses were designed to answer the question of interest. The primary concern with directness was due to study design and specificity of food sources. Specifically, multiple studies included high-saturated fat run-in periods or between-group differences in saturated fat content outside the meat products, while others examined meat types that are not frequently consumed in the U.S.

###### Generalizability

There were substantial concerns with generalizability due to limited diversity in race and/or ethnicity and socioeconomic position in the studies that did report these data. These data were not reported in most studies in this body of evidence. Roughly half of the studies were conducted in the U.S.

#### Red meat compared to fish and seafood

##### Description of the evidence

Sixteen articles compared red meat to fish and seafood in adults and older adults: 1 NCC^57^ and 15 PCS^34,38,53,54,56,59,71,80–84,86–88^. Evidence from red meat compared to fish and seafood in adults and older adults and risk of cardiovascular disease is summarized in Table 61. Risk of bias assessments for each article are summarized in Table 62.

###### Population

Mean baseline age ranged from 36 to 62 years; three articles^57,80,83^ were conducted in participants with a mean age ≥60 years. Three articles^34,80,81^ enrolled only females, 1 article^53^ enrolled only males, 2 articles^56,59^ were >70% female, and 1 article^83^ was 88% male; all other articles had relatively even distribution of male and female enrollment. Sample sizes ranged from N=668 to N=409,885; two studies^57,88^ had analytic sample sizes less than 10,000 participants.

Articles included in this body of evidence were conducted in the following countries:

- United States: 8 articles^34,38,53,54,59,80,83,87^
- Denmark: 3 articles^71,82,86^
- France: 1 article^81^
- The Netherlands: 1 article^57^
- UK: 1 article^84^
- Multiple European countries: 1 article^56^
- Multiple countries (Finland, UK, New Zealand, Australia): 1 article^88^

Nine articles were conducted in predominately White/Caucasian samples.^34,38,53,54,59,80,83,84,88^ One article^87^ had more diverse racial and/or ethnic representation: 69% non-Hispanic White, 24% non-Hispanic Black, 4.5% Hispanic, 2% Chinese, <1% Other. Six articles did not report data on race and/or ethnicity.^56,57,71,81,82,86^

Five articles were conducted in primarily well-educated samples.^34,53,54,59,71^ Ten articles were diverse in terms of participant education and/or income levels.^38,56,57,80–84,86,87^ One article did not report data on socioeconomic position.^88^

One article enrolled participants with overweight or obesity and prediabetes.^88^ All other articles enrolled participants who were generally healthy and without chronic disease.

###### Intervention/exposure and comparator

The intervention or exposure of interest was red meat, which included unprocessed red meat, processed red meat, or total red meat (unprocessed and processed red meat combined). Eight articles^38,53,71,82–84,86,87^ examined unprocessed red meat consumption, 10 articles^38,53,57,71,81–83,86–88^ examined processed red meat consumption, and 9 articles^34,53,54,56,59,71,80,83,86^ examined consumption of total red meat. Zhu et al^88^ included luncheon meat made from poultry in their measure of “processed meat”.

The comparator of interest was fish and seafood:

- Fish and/or seafood: 7 articles^34,53,54,59,71,80,88^
  ○ “Canned tuna, dark- and light-fleshed fish, and breaded fish”^34,54^
  ○ “Canned tuna fish; breaded fish cakes, pieces, or fish sticks; other fish (e.g., cod, haddock, halibut); dark meat fish (e.g. mackerel, salmon, sardines, bluefish, swordfish”^53^
  ○ “All types of fish and shellfish, such as raw fish, cold cuts, roe, shellfish and prepared/cooked fish”^71^
  ○ “Fatty fish, fish products, low-fat fish, canned fatty fish, canned low-fat fish, seafoods, crustaceans including lobster and shrimps”^88^
  ○ “Dark meat fish, other fish, shrimp, lobster, and canned tuna”^59^
  ○ “Fish and other seafood”^80^
- Fish separated into “lean” (e.g., white fish, low content of omega-3 PUFA) or “fatty” (e.g., high content of omega-3 PUFA): 4 articles^56,81,82,86^
- Did not provide details on fish or seafood: 5 articles^38,57,83,84,87^

Most studies measured red meat consumption with a validated FFQ; 1 article^88^ used a 4-day diet record. Nine articles^56,57,71,80,82–84,86,87^ measured red meat consumption at baseline only and 7 articles^34,38,53,54,59,81,88^ assessed diet over multiple time points. Most studies modeled the substitution of red meat with fish and seafood as a continuous measure (e.g., 1 serving per day substitution or 150 grams per week substitution).

###### Outcomes

One article collected fasting blood samples and examined mean change in triglycerides per year over 3 years.^88^ No articles provided data on LDL-C or HDL-C. Two articles examined self-reported hypertension (based on annual questionnaires^59^ or date of diagnosis and use of medication^81^) over a 18- to 26-year follow-up.

Nine articles examined CVD morbidity (stroke^54,82^; fatal or non-fatal ischemic heart disease^56^; fatal and non-fatal MI, CHD, or CVD^34,38,53,83,86,87^) collected from national registries and medical records. Average follow-up duration ranged for CVD morbidity from 4 to 30 years.

Four articles examined CVD mortality using death certificates, medical records, autopsy reports, or linkage to national registries; average follow-up duration for CVD mortality ranged from 8 to 18 years.^57,71,80,84^

##### Synthesis of the evidence

Synthesis of the evidence comparing red meat to fish and seafood focused on CVD morbidity due inadequate data on CVD mortality, triglyceride levels, and blood pressure and no data on LDL-C or HDL-C. The conclusion statement is therefore based solely on substitution analyses from prospective cohort studies. No studies exclusively enrolled an older adult population, though many included older adults. As a result, there is not a separate conclusion statement for older adults, and the conclusion statement drawn applies to all adults, including older adults.

Findings on the relationship between substituting red meat with fish or seafood and risk of CVD morbidity were considerably mixed. Roughly two-thirds of the analyses showed no relationship, while the remaining analyses were a mix of those finding a significant benefit of substituting red meat with fish overall and those with stratified analyses showing mixed results. When stratified by sex, substituting red meat with fish appeared to be beneficial or non-significant for women but non-significant or detrimental for men.^59,86^

There was notable variability in whether studies looked at fish and seafood combined, fish overall, or specific types of fish (e.g., fatty, lean), which also limited the ability to synthesize.

##### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on red meat compared to fish and seafood by adults and older adults (Table 18).

Table 18 Conclusion statement and grade for red meat compared to fish and seafood in adults and older adults and risk of cardiovascular disease

Conclusion Statement | Substituting processed or unprocessed red meat with fish or seafood by adults and older adults may not be associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 9 articles: all PCS (25 comparisons, all substitution analyses)
Consistency | Some concerns with consistency. Roughly two-thirds of analyses showed no relationship, while the remaining were mixed.
Precision | Few concerns with precision. Sample sizes were large, and confidence intervals were narrow.
Risk of bias | Some concerns with risk of bias, particularly due to unadjusted confounding, exposure measurement, missing data, and not having preregistered data analysis plans
Directness | Some concerns with directness, primarily due to the modeling approach used for these substitution analyses and the lack of trial data
Generalizability | Substantial concerns with generalizability due to limited diversity in race and/or ethnicity and socioeconomic position. Half of the studies were conducted in the U.S.

###### Assessment of the evidence

The body of evidence underlying the conclusion statement included 25 comparisons (all substitution analyses) from 9 PCS. The strength of the evidence was graded based on an assessment of five grading elements, as described below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, the body of evidence included studies with null findings, so there was less concern of publication bias.

###### Consistency

Findings on substituting red meat with fish or seafood on CVD morbidity were mixed, but roughly two-thirds indicated no relationship. The remaining articles showed a mix of significant and non-significant relationships.

###### Precision

There were few concerns with precision. Sample sizes were large across the observational evidence, and confidence intervals were narrow.

###### Risk of bias

There were some concerns with risk of bias, primarily in the areas of unadjusted confounding, exposure measurement (e.g., measuring only once), inadequate information on or adjustment for missing data, and not having a preregistered data analysis plan.

###### Directness

The analyses were designed to answer the question of interest. Therefore, the primary concern with directness was the reliance of substitution analyses and the lack of other observational or trial data on this relationship.

###### Generalizability

Most studies in this body of evidence considered predominantly White/Caucasian populations, limiting generalizability to other racial and/or ethnic groups. There was more diversity in socioeconomic position across studies, and all but one enrolled generally healthy populations without chronic disease. Roughly half of the studies were conducted in the U.S.

#### Red meat compared to eggs

##### Description of the evidence

Ten articles compared red meat to eggs in adults and older adults: all PCS.^38,53,54,56,57,81,83,87–89^ Evidence from red meat compared to eggs in adults and older adults and risk of cardiovascular disease is summarized in Table 63. Risk of bias assessments for each article are summarized in Table 64.

###### Population

Mean baseline age ranged from 52 to 62 years; three articles^57,83,89^ were conducted in participants with a mean age ≥60 years. One article^81^ enrolled only females, 1 article^53^ enrolled only males, and 1 article^83^ was 88% male; all other articles had relatively even distribution of male and female enrollment. Sample sizes ranged from N=668 to N=521,120; one study^88^ had an analytic sample size less than 10,000 participants.

Articles included in this body of evidence were conducted in the following countries:

- United States: 6 articles^38,53,54,83,87,89^
- France: 1 article^81^
- The Netherlands: 1 article^57^
- Multiple European countries: 1 article^56^
- Multiple countries (Finland, UK, New Zealand, Australia): 1 article^88^

Six articles were conducted in predominately White/Caucasian samples.^38,53,54,83,88,89^ One article^87^ had more diverse racial and/or ethnic representation: 69% non-Hispanic White, 24% non-Hispanic Black, 4.5% Hispanic, 2% Chinese, <1% Other. Three articles did not report data on race and/or ethnicity.^56,57,81^

Two articles were conducted in primarily well-educated samples.^53,54^ Seven articles were diverse in terms of participant education and/or income levels.^38,56,57,81,83,87,89^ One article did not report data on socioeconomic position.^88^

One article enrolled participants with overweight or obesity and prediabetes.^88^ All other articles enrolled participants who were generally healthy and without chronic disease.

###### Intervention/exposure and comparator

The intervention or exposure of interest was red meat, which included unprocessed red meat, processed red meat, or total red meat (unprocessed and processed red meat combined). Five articles^38,53,83,87,89^ examined unprocessed red meat consumption, 8 articles^38,53,57,81,83,87–89^ examined processed red meat consumption, and 5 articles^53,54,56,83,89^ examined consumption of total red meat. Zhu et al^88^ included luncheon meat made from poultry in their measure of “processed meat”.

The comparator of interest was eggs:

- Whole egg: 5 articles^53,54,56,87,89^
- “Eggs, egg products, egg dishes”: 1 article^88^
- Did not provide details on eggs: 4 articles^38,57,81,83^

Most studies measured red meat consumption with a validated FFQ; 1 article^88^ used a 4-day diet record. Five articles^56,57,83,87,89^ measured red meat consumption at baseline only and 5 articles^38,53,54,81,88^ assessed diet over multiple time points. All studies modeled the substitution of red meat with eggs (or vice versa) as a continuous measure (e.g., 1 serving per day substitution).

###### Outcomes

One article collected fasting blood samples and examined mean change in triglycerides per year over 3 years.^88^ No articles provided data on LDL-C or HDL-C. Thao et al^81^ examined incidence of self-reported hypertension based on date of diagnosis and use of medication over an 18-year follow-up period.

Six articles examined CVD morbidity (stroke^54^; fatal or non-fatal ischemic heart disease^56^; fatal and non-fatal CHD or CVD^38,53,83,87^), which was collected from medical records, patient registries, autopsy data, or death certificates. Average follow-up duration for CVD morbidity ranged from 4 to 30 years.

Two articles assessed CVD mortality using linkage to national registries; average follow-up duration for CVD mortality ranged from 10 to 16 years.^57,89^

##### Synthesis of the evidence

Synthesis of the evidence comparing red meat to eggs focused on CVD morbidity due inadequate data on CVD mortality, triglyceride levels, and blood pressure and no data on LDL-C or HDL-C. The conclusion statement is therefore based solely on substitution analyses from prospective cohort studies. No studies exclusively enrolled an older adult population, though many included older adults. As a result, there is not a separate conclusion statement for older adults, and the conclusion statement drawn applies to all adults, including older adults.

Most analyses showed no relationship between substituting unprocessed or processed or red meat with eggs and risk of CVD morbidity. One study showed a beneficial association when substituting processed red meat with eggs on risk of CVD morbidity and an association with total red meat trending in the same direction.^53^ A second study that only looked at total red meat also found a significant, beneficial association when substituting with eggs.^56^ A third study substituted unprocessed and processed red meat for eggs and found trending results in the opposite direction for unprocessed red meat, such that substituting eggs with unprocessed red meat trended toward an association with lower CVD morbidity. There was no relationship in substituting eggs with processed red meat.^87^ All other analyses showed no relationship between substitutions of red meat with eggs and risk of CVD morbidity.

##### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on red meat compared to eggs by adults and older adults (Table 19).

Table 19 Conclusion statement and grade for red meat compared to eggs in adults and older adults and risk of cardiovascular disease

Conclusion Statement | Substituting processed or unprocessed red meat with eggs by adults and older adults is not associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 7 articles: all PCS (12 comparisons, all substitution analyses)
Consistency | Some concerns with consistency. Most analyses showed no relationship.
Precision | Few concerns with precision. Sample sizes were large, and confidence intervals were narrow.
Risk of bias | Substantial concerns with risk of bias, particularly due to unadjusted confounding, exposure measurement, missing data, and not having preregistered data analysis plans
Directness | Some concerns with directness, primarily due to the modeling approach used for these substitution analyses and the lack of trial data
Generalizability | Substantial concerns with generalizability. Although most studies were conducted in the U.S., there was limited diversity in race and/or ethnicity and socioeconomic position.

###### Assessment of the evidence

The body of evidence underlying the conclusion statement included 12 comparisons (all substitution analyses) from 7 PCS. The strength of the evidence was graded based on an assessment of five grading elements, as described below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, the body of evidence included studies with null findings, so there was less concern of publication bias.

###### Consistency

Findings on substituting red meat with eggs on CVD morbidity consistently showed no relationship, with only a small number of analyses indicating a beneficial relationship.

###### Precision

There were few concerns with precision. Sample sizes were large across the observational evidence, and confidence intervals were narrow.

###### Risk of bias

There were substantial concerns with risk of bias, primarily in the areas of unadjusted confounding, exposure measurement (e.g., measuring only once), inadequate information on or adjustment for missing data, and not having a preregistered data analysis plan.

###### Directness

The analyses were designed to answer the question of interest. Therefore, the primary concern with directness was the reliance of substitution analyses and the lack of other observational or trial data on this relationship.

###### Generalizability

Most studies in this body of evidence were conducted in the U.S. but considered predominantly

White/Caucasian populations or did not provide data on race and/or ethnicity, limiting generalizability to other racial and/or ethnic groups. There was more diversity in socioeconomic position across studies, and all but one enrolled generally healthy populations without chronic disease.

#### White meat compared to plant-based foods

##### Description of the evidence

Eight articles compared white meat to plant-based foods (e.g., plant sources of protein such as beans, peas, lentils, nuts, seeds, or soy; fruit and vegetables; grains and cereals) in adults and older adults: 1 crossoverRCT^58^ and 7 PCS^34,38,54,64,80,85,87^. Evidence from white meat compared to plant-based foods in adults and older adults and risk of cardiovascular disease is summarized in Table 65. Risk of bias assessments for each article are summarized in Table 66 (RCT) and Table 67 (observational).

###### Population

Mean baseline age ranged from 44 to 62 years; one article^80^ was conducted in participants with a mean age ≥60 years. Two articles^34,80^ enrolled only females; all other articles had relatively even distribution of male and female enrollment. The trial^58^ had an analytic sample size of N=113. Observational studies had sample sizes ranging from N=12,066 to N=127,160.

Articles included in this body of evidence were conducted in the following countries:

- United States: 6 articles^34,38,54,58,80,87^
- Denmark: 1 article^85^
- Singapore: 1 article^64^

Four articles were conducted in predominately White/Caucasian samples.^34,38,54,80^ Three articles had more diverse racial and/or ethnic representation: 55% White, 20% Asian, 12% African American, 13% Other^58^; 45% Chinese, 27% Malay, 28% Indian^64^; 69% non-Hispanic White, 24% non-Hispanic Black, 4.5% Hispanic, 2% Chinese, <1% Other^87^. One article did not report data on race and/or ethnicity.^85^

Two articles were conducted in primarily well-educated samples.^34,54^ Four articles were diverse in terms of participant education and/or income levels.^38,64,80,87^ Two articles did not report data on socioeconomic position.^58,85^

All articles enrolled participants who were generally healthy and without chronic disease.

###### Intervention/exposure and comparator

The intervention or exposure of interest was white meat, which included unprocessed white meat, processed white meat, or total white meat (unprocessed and processed white meat combined). Five articles^38,58,80,85,87^ examined unprocessed red meat consumption, no articles examined processed red meat consumption, and 3 articles^34,54,64^ examined consumption of total white meat.

The comparator of interest was plant-based foods (e.g., plant sources of protein such as beans, peas, lentils, nuts, seeds, or soy; fruit and vegetables; grains and cereals):

- Nuts: 5 articles^34,38,54,80,87^
- Beans: 1 article^34^
- Legumes: 2 articles^38,87^
- Non-meat proteins (legumes, nuts, grains, isoflavone-free soy products): 1 article^58^
- Vegetables: 1 article^85^
- Potatoes: 1 article^85^
- Whole grains: 1 article^87^
- Refined grains: 1 article^64^

The RCT^58^ compared lean white meat (8% energy from chicken and 4% energy from turkey) to non-meat sources of protein (legumes, nuts, grains, isoflavone-free soy products); the intervention duration was 4 weeks separated by a 2- to 7-week washout period.

All observational studies measured white meat consumption with a validated FFQ. Four articles^64,80,85,87^ measured white meat consumption at baseline only and 3 articles^34,38,54^ assessed diet over multiple time points. Most observational studies modeled the substitution of white meat with plant-based foods as a continuous measure (e.g., 1 serving per day substitution or 150 grams per week substitution); Lim et al^64^ modeled the substitution of refined grains with poultry.

###### Outcomes

The trial measured fasting blood lipids (LDL-C, HDL-C, and triglycerides) and blood pressure at baseline and after the 4-week intervention.

Six articles^34,38,54,64,85,87^ examined CVD morbidity (stroke^54^; fatal and non-fatal MI, CHD, or CVD^34,38,85,87^), which was often collected from medical records and patient registries; Lim et al^64^ examined the incidence of major adverse cardiovascular events, which included nonfatal acute MI, nonfatal stroke, and CVD mortality. Average follow-up duration for CVD morbidity ranged from 10 to 26 years.

One article assessed CVD mortality using death certificates, medical records, autopsy reports, or linkage to national registries over an 18-year follow-up period.^80^

##### Synthesis of the evidence

Synthesis of the evidence comparing white meat to plant-based foods focused on CVD morbidity due inadequate data on CVD mortality, blood lipids, and blood pressure. The conclusion statement is therefore based solely on substitution analyses from prospective cohort studies. No studies exclusively enrolled an older adult population, though many included older adults. As a result, there is not a separate conclusion statement for older adults, and the conclusion statement drawn applies to all adults, including older adults.

Despite the numerous food types considered in this plant-based foods comparator, all but one analysis on the relationship between substituting white meat with plant-based foods on CVD morbidity were non-significant. One study found a beneficial relationship when substituting white meat with nuts, specifically^87^; and the same study showed a trending relationship for whole grains and legumes, while a second study showed trending results for potatoes and vegetables.^85^ Findings were otherwise non-significant across a range of plant-based foods, including beans, grains, nuts, legumes, and potatoes.

##### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on white meat compared to plant-based foods by adults and older adults (Table 20).

Table 20 Conclusion statement and grade for white meat compared to plant-based foods in adults and older adults and risk of cardiovascular disease

Conclusion Statement | Substituting white meat with plant-based foods by adults and older adults is not associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 6 articles: all PCS (11 comparisons, all substitution analyses)
Consistency | Some concerns with consistency. Most findings were null.
Precision | Few concerns with precision. Sample sizes were large, and confidence intervals were narrow.
Risk of bias | Some concerns with risk of bias, particularly due to unadjusted confounding, missing data, and not having preregistered data analysis plans
Directness | Some concerns with directness, primarily due to the modeling approach used for these substitution analyses and the lack of trial data
Generalizability | Some concerns with generalizability. Although most studies were conducted in the U.S., not all populations were diverse in race and/or ethnicity or socioeconomic position.

###### Assessment of the evidence

The body of evidence underlying the conclusion statement included 11 comparisons (all substitution analyses) from 6 PCS. The strength of the evidence was graded based on an assessment of five grading elements, as described below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, the body of evidence included studies with null findings, so there was less concern of publication bias.

###### Consistency

Findings on substituting white meat with plant-based food sources on CVD morbidity consistently showed no relationship. Only one analysis indicated significant association indicating a beneficial relationship between substituting plant-based foods for white meat, and a small number of analyses showed trending results in the same direction. Though there was variability in the plant-based food sources examined, results overall remained consistent.

###### Precision

There were few concerns with precision. Sample sizes were large across the observational evidence, and confidence intervals were narrow.

###### Risk of bias

There were some concerns with risk of bias, primarily in the areas of unadjusted confounding, inadequate information on or adjustment for missing data, and not having a preregistered data analysis plan.

###### Directness

The analyses were designed to answer the question of interest. Therefore, the primary concern with directness was the reliance of substitution analyses and the lack of other observational or trial data on this relationship.

###### Generalizability

The articles including in this body of evidence were primarily conducted in the U.S. and had greater racial and/or ethnic diversity than the other areas of evidence on meat. Roughly half considered a racially and/or ethnically diverse sample, and over half considered a population with diverse socioeconomic position. All studies enrolled generally healthy populations without chronic disease.

#### White meat compared to fish and seafood

##### Description of the evidence

Seven articles compared white meat to fish and seafood in adults and older adults: all PCS.^34,38,54,59,82,86,87^ Evidence from white meat compared to fish and seafood in adults and older adults and risk of cardiovascular disease is summarized in Table 68. Risk of bias assessments for each article are summarized in Table 69.

###### Population

Mean baseline age ranged from 36 to 58 years. One article^34^ enrolled only females and 1 article^56^ was 74% female; all other articles had relatively even distribution of male and female enrollment. Sample sizes ranged from N=12,066 to N=188,518.

Articles included in this body of evidence were conducted in the following countries:

- United States: 5 articles^34,38,54,59,87^
- Denmark: 2 articles^82,86^

Four articles were conducted in predominately White/Caucasian samples.^34,38,54,59^ One article had more diverse racial and/or ethnic representation: 69% non-Hispanic White, 24% non-Hispanic Black, 4.5% Hispanic, 2% Chinese, <1% Other.^87^ Two articles did not report data on race and/or ethnicity.^82,86^

Three articles were conducted in primarily well-educated samples.^34,54,59^ Four articles were diverse in terms of participant education and/or income levels.^38,82,86,87^

All articles enrolled participants who were generally healthy and without chronic disease.

###### Intervention/exposure and comparator

The intervention or exposure of interest was white meat, which included unprocessed white meat, processed white meat, or total white meat (unprocessed and processed white meat combined). Five articles^38,59,82,86,87^ examined unprocessed red meat consumption, no articles examined processed red meat consumption, and 2 articles^34,54^ examined consumption of total white meat.

The comparator of interest was fish and seafood:

- Fish (“canned tuna, dark- and light-fleshed fish, and breaded fish”): 2 articles^34,54^
- Seafood (“dark meat fish, other fish, shrimp, lobster, and canned tuna”): 1 article^59^
- Fish separated into “lean” or “fatty” based on omega-3 PUFA content: 2 articles^82,86^
- Did not provide details on fish: 2 articles^38,87^

All studies measured white meat consumption with a validated FFQ. Three articles^82,86,87^ measured white meat consumption at baseline only and 4 articles^34,38,54,59^ assessed diet over multiple time points. All observational studies modeled the substitution of white meat with fish or seafood as a continuous measure (e.g., 1 serving per day substitution or 150 grams per week substitution).

###### Outcomes

One article^59^ examined incidence of self-reported hypertension based on annual questionnaires over a 20- to 26-year follow-up period. No articles examined blood lipids (LDL-C, HDL-C, triglycerides).

Six articles examined CVD morbidity (stroke^54,82^; fatal and non-fatal MI or CVD^34,38,86,87^) collected from national registries and medical records. Average follow-up duration for CVD morbidity ranged from 13 to 26 years.

No articles examined CVD mortality.

##### Synthesis of the evidence

Synthesis of the evidence comparing white meat to fish and seafood focused on CVD morbidity due inadequate data on blood pressure and no data on CVD mortality or blood lipids. The conclusion statement is therefore based solely on substitution analyses from prospective cohort studies. No studies exclusively enrolled an older adult population, though many included older adults. As a result, there is not a separate conclusion statement for older adults, and the conclusion statement drawn applies to all adults, including older adults.

All analyses examining the relationship between substituting white meat with fish or seafood and CVD morbidity were non-significant, though one study provided stratified analyses that showed a significant benefit of substituting white meat with fatty fish for women but not men^86^ and another showed a trending relationship for the full sample in the same direction.^87^

Similar to the issues noted with red meat and fish/seafood, there was notable variability in whether studies looked at fish and seafood combined, fish overall, or specific types of fish (e.g., fatty, lean). However, unlike with red meat, findings for white meat were consistent across fish and seafood types.

##### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on white meat compared to fish or seafood by adults and older adults (Table 21).

Table 21 Conclusion statement and grade for white meat compared to fish and seafood in adults and older adults and risk of cardiovascular disease

Conclusion Statement | Substituting white meat with fish or seafood by adults and older adults is not associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 6 articles: all PCS (10 comparisons, all substitution analyses)
Consistency | Few concerns with consistency. Most analyses showed no relationship.
Precision | Few concerns with precision. Sample sizes were large, and confidence intervals were narrow.
Risk of bias | Some concerns with risk of bias, particularly due to unadjusted confounding, missing data, and not having preregistered data analysis plans
Directness | Some concerns with directness, primarily due to the modeling approach used for these substitution analyses and the lack of trial data
Generalizability | Substantial concerns with generalizability due to limited diversity in race and/or ethnicity and socioeconomic position. Over half of the studies were conducted in the U.S.

###### Assessment of the evidence

The body of evidence underlying the conclusion statement included 10 comparisons (all substitution analyses) from 6 PCS. The strength of the evidence was graded based on an assessment of five grading elements, as described below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, the body of evidence included studies with null findings, so there was less concern of publication bias.

###### Consistency

Findings on substituting white meat with fish or seafood on CVD morbidity consistently showed no relationship. Only one analysis showed a significant benefit of substituting white meat with fish but for women only, not men.

###### Precision

There were few concerns with precision. Sample sizes were large across the observational evidence, and confidence intervals were narrow.

###### Risk of bias

There were some concerns with risk of bias, primarily in the areas of unadjusted confounding, inadequate information on or adjustment for missing data, and not having a preregistered data analysis plan.

###### Directness

The analyses were designed to answer the question of interest. Therefore, the primary concern with directness was the reliance of substitution analyses and the lack of other observational or trial data on this relationship.

###### Generalizability

Most studies in this body of evidence considered predominantly white/Caucasian populations or did not provide data on race and/or ethnicity, limiting generalizability to other racial and/or ethnic groups. There was more diversity in socioeconomic position across studies. All studies enrolled generally healthy populations without chronic disease. Over half of the studies were conducted in the U.S.

#### Meat compared to plant-based foods in trials

##### Description of the evidence

Five trials compared the effect of meat consumption to plant-based foods in adults and older adults: 1 cluster-RCT^62^, 2 parallel-RCT^63,73^, and 2 crossover-RCT^58,67^. Evidence from the effect of meat consumption compared to plant-based foods in adults and older adults and risk of cardiovascular disease is summarized in Table 70. Risk of bias assessments for each article are summarized in Table 71.

###### Population

Mean baseline age ranged from 44 to 73 years; two articles^62,63^ were conducted in participants with a mean age ≥60 years. One trial^62^ enrolled only females; all other articles had 62-88% female enrollment. Analytic sample sizes of the study groups ranged from N=33 to N=154.

Articles included in this body of evidence were conducted in the following countries:

- United States: 3 articles^58,67,73^
- Australia: 2 articles^62,63^

Two articles were conducted in predominately White/Caucasian samples.^63,67^ Two articles had more diverse racial and/or ethnic representation: 55% White, 20% Asian, 12% African American, 13% Other^58^; 45% White/Caucasian, 53% African American, 2% Hispanic^73^. One article did not report data on race and/or ethnicity.^62^

Most articles did not report data on socioeconomic position.^58,62,67,73^ One article was diverse in terms of participant education levels.^63^

One trial^73^ had inclusion criteria for BMI 25-40 kg/m^2^ and another trial^67^ recruited individuals with metabolic syndrome and/or prediabetes. One trial was conducted in generally healthy adults.^58^

###### Intervention and comparator

The intervention of interest was red meat, white meat, or processed meat. All 5 articles examined unprocessed red meat; no articles examined processed red meat or total red meat (unprocessed and processed red meat combined). One article examined unprocessed white meat^58^; no articles examined processed white meat or total white meat (unprocessed and processed white meat combined).

The comparator of interest was plant-based foods (e.g., beans, nuts, vegetables, mushrooms, grains). The details for each trial are as follows:

- Bergeron et al^58^ conducted a 4-week trial and compared lean red meat (11% energy from lean cuts of grain-finished beef and 1% energy from lean cuts of pork) and lean white meat (8% energy from chicken and 4% energy from turkey) consumption to non-meat sources of protein (legumes, nuts, grains, isoflavone-free soy products).
- Daly et al^62^ conducted a 4-month trial in which one group consumed lean red meat (160 grams per day of veal, lamb, or beef) or carbohydrates (rice, pasta, or potato) with a focus on larger servings of bread, cereals, rice and vegetables and smaller servings of protein foods (e.g., meat and fish); both groups consumed study foods 6 days per week. All participants received individual counseling sessions with a dietitian and prescribed an individually tailored and supervised progressive resistance and balance-agility training program.
- Formica et al^63^ conducted a 24-week trial in which participants consumed either lean red meat (160 grams per day of veal, lamb, or beef) or carbohydrates (rice, pasta, or potato) on 3 nonconsecutive days per week. All participants received an individually tailored and supervised multicomponent exercise program; those in the red meat group were advised to follow their usual diet and those in the carbohydrate group were instructed to consume more carbohydrates and less meat.
- Maki et al^67^ conducted a 28-day trial in which participants with overweight/obesity and prediabetes and/or metabolic syndrome consumed either a diet providing <40 grams per day of red meat (to reflect the USDA Healthy U.S.-Style Eating Pattern) or a diet modified to include an additional 150 grams per day of lean, unprocessed beef as an isocaloric replacement for carbohydrate.
- Poddar et al^73^ conducted a 12-month trial (6-month weight loss and 6-month weight maintenance) in which participants consumed either lean ground beef compared to another group that substituted 8 ounces of white button mushrooms for red meat by incorporating in sauteed vegetables, “burgers”, and other normally meat-containing dishes; both groups consumed study foods 3 meals each week. All participants were prescribed an energy-deficit diet (500 kilocalorie per day) in the first 6 months and received dietary instruction; the mushroom group received additional instruction on using mushroom substitutes.

###### Outcomes

All trials measured fasting blood lipids (LDL-C, HDL-C, and triglycerides) and blood pressure at baseline and after the intervention. Intervention duration for the crossover trials was 4 weeks (with a ≥2 week washout)^58,67^; the cluster trial^63^ was 4 months. One parallel trial was 24 weeks^73^ and another was 12 months.^73^

##### Synthesis of the evidence

Synthesis of the trial data examining replacement of meat with plant-based foods focused on blood lipids and blood pressure. No studies exclusively enrolled an older adult population, though many included older adults. As a result, there is not a separate conclusion statement for older adults, and the conclusion statement drawn applies to all adults, including older adults.

As noted above, the trials included a range of plant-based foods, including plant sources of protein, refined grains and starches, potatoes, and mushrooms. Most trials showed no differences in blood lipids or blood pressure across the intervention period, which ranged from 4 weeks to 12 months. The trial with the least quality concerns found the meat condition raised both LDL-C and HDL-C but did not affect triglyceride or blood pressure levels.^58^ Variability in results was not related to trial duration.

The quality of trial design varied considerably across this small body of evidence. The primary areas of concern included lack of directness in study design, high attrition, poor adherence, and funding source.

Overall, limitations in study design, variability in the populations and study foods included, and inconsistency in findings prevented a conclusion statement from being drawn for the trial data.

##### Conclusion statement and grade

The Committee was not able to develop a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on meat consumption compared to plant-based foods by adults and older adults (Table 22). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias.

Table 22 Conclusion statement and grade for effect of meat consumption compared to plant-based foods in adults and older adults and risk of cardiovascular disease

Conclusion Statement | A conclusion statement cannot be drawn about the effects of unprocessed meat consumption compared to plant-based foods by adults and older adults on blood lipids or blood pressure because of substantial concerns with consistency of the comparator, directness, risk of bias, and precision in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 5 articles: all RCT
Rationale | Substantial concerns about study design and inconsistency in study foods and findings prevented synthesis.

#### Meat with different amounts of saturated fat

##### Description of the evidence

Three articles compared meat with different amounts of saturated fat in adults and older adults: 2 crossover-RCT^61,66^ and 1 PCS^86^. Evidence comparing meat with different amounts of saturated fat in adults and older adults and risk of cardiovascular disease is summarized in Table 72. Risk of bias assessments for each article are summarized in Table 73 (RCT) and Table 74 (observational).

###### Population

Mean baseline age ranged from 40 to 56 years. Both trials enrolled only males; the observational study had relatively even distribution of male and female enrollment. Analytic sample sizes of the study groups among the trials ranged from N=18 to N=25; the observational study had a sample size of N=55,171.

Articles included in this body of evidence were conducted in the following countries:

- United States: 1 article^66^
- Denmark: 1 article^86^
- Spain: 1 article^61^

All articles did not report data on race and/or ethnicity. Both trials did not report data on socioeconomic position. The observational study was diverse in terms of participant education levels.^86^

One trial had inclusion criteria for BMI 25-40 kg/m^2^ and total cholesterol >200 mg/dL.^61^ All other articles enrolled participants who were generally healthy and without chronic disease.

###### Intervention/exposure and comparator

The intervention or exposure of interest was red meat, white meat, or processed meat. Two articles^66,86^ examined unprocessed red meat and 1 article^61^ examined processed meat. No articles examined white meat.

The comparator was a similar meat source with different amounts of saturated fatty acids due to different amounts of total fat. The observational study measured unprocessed meat consumption at baseline using a validated FFQ and compared fatty meat (>10 grams fat per 100 grams) with a 150 gram per week substitution of lean meat (≤10 grams fat per 100 grams).^86^ A 4-week trial^66^ compared high-fat (24% fat) to low-fat (5% fat) ground beef, and a 5-week trial^61^ compared normal-fat frankfurters and pâté (18% and 30% fat, respectively) to reduced-fat versions (15% fat each).

###### Outcomes

Both trials measured fasting LDL-C at baseline and after the intervention, but only 1 trial^59^ provided data on fasting HDL-C and triglycerides. One trial also measured blood pressure.^61^ Intervention duration for both trials was 4-5 weeks (with a 4-week washout).

One article examined CVD morbidity (fatal and non-fatal MI) collected from national registries over a 13-year follow-up duration.

No articles examined CVD mortality.

##### Synthesis of the evidence

Across this small body of evidence, there was substantial variability in study design, food sources examined, and outcomes measured. The 2 trials examined similar comparisons but markedly different food sources. Lytle et al^66^ examined blood lipids and found no difference between 5-week high-fat and low-fat ground beef conditions for LDL-C, HDL-C, or triglycerides. The second RCT compared 3, 4-week processed meat conditions: normal-fat frankfurters and pâté, reduced-fat versions, and Omega-3-enriched versions.^61^ They found no significant differences between normal-fat and reduced-fat conditions for LDL-C or blood pressure or between normal-fat and Omega-3-enriched versions for blood pressure. The single significant finding indicated higher LDL-C in the normal-fat compared to Omega-3-enriched conditions. The PCS compared fatty to lean unprocessed red meats and found no association with CVD morbidity.^86^

Evidence on red meat with different amounts of saturated fat varied too substantially in food sources and outcomes to allow synthesis, and no conclusion could be drawn. No conclusion could be drawn on white meat with different amounts of saturated fat because there was no evidence.

##### Conclusion statements and grades

The Committee was not able to develop conclusion statements to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence comparing meat with different amounts of saturated fat (Table 23). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias.

Table 23 Conclusion statements and grades for comparing meat with different amounts of saturated fat in adults and older adults and risk of cardiovascular disease

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of red meat with different amounts of saturated fat by adults and older adults and risk of cardiovascular disease because there is not enough evidence available. | A conclusion statement cannot be drawn about the relationship between consumption of white meat with different amounts of saturated fat by adults and older adults and risk of cardiovascular disease because there is no evidence available.
Grade | Grade Not Assignable | Grade Not Assignable
Body of Evidence | 3 articles: 2 RCT, 1 PCS | 0 articles
Rationale | Substantial variability in food sources examined prevented synthesis. | There was no evidence available examining this relationship in adults and older adults.

#### Processed meat compared to unprocessed meat

##### Description of the evidence

Six articles compared processed meat with unprocessed meat in adults and older adults: 1 crossover-RCT^70^ and 5 PCS^38,75,81,86,87^. Evidence comparing processed meat with unprocessed meat in adults and older adults and risk of cardiovascular disease is summarized in Table 75. Risk of bias assessments for each article are summarized in Table 76 (RCT) and Table 77 (observational).

###### Population

Mean baseline age ranged from 37 to 56 years. One PCS enrolled only females^81^; all other articles had relatively even distribution of male and female enrollment. The analytic sample size of the study groups in the trials was N=54. Observational studies had sample sizes ranging from N=12,066 to N=55,171.

Articles included in this body of evidence were conducted in the following countries:

- United States: 2 articles^38,87^
- Spain: 2 articles^70,75^
- France: 1 article^81^
- Denmark: 1 article^86^

Four articles did not report data on race and/or ethnicity.^70,75,81,86^ One article was conducted in a predominately White/Caucasian sample.^38^ One article had more diverse racial and/or ethnic representation: 69% non-Hispanic White, 24% non-Hispanic Black, 4.5% Hispanic, 2% Chinese, <1% Other.^87^

All observational articles provided data on participant education.^38,75,81,86,87^ The trial did not report data on socioeconomic position.^58,62,67,73^

All articles from observational studies enrolled participants who were generally healthy and without chronic disease. The trial recruited participants with stage 1 hypertension, hypercholesterolemia, and/or elevated blood glucose.^70^

###### Intervention/exposure and comparator

The intervention or exposure of interest was processed meat. The comparator was unprocessed meat. All articles compared processed red meat to unprocessed red meat.

All observational studies measured meat consumption with a validated FFQ; 3 articles^75,86,87^ measured meat consumption at baseline only and 2 articles^38,81^ assessed diet over multiple time points.

The trial compared boiled or dried ham consumption for 4 weeks with a 2-week washout; participants were asked to avoid plant sterols, cured meat, chips, pickles, dry soups to avoid the excessive consumption of salt and other cured meat products.^70^

###### Outcomes

The trial measured fasting blood lipids (LDL-C, HDL-C, and triglycerides) and blood pressure at baseline and after the intervention. Two PCS examined self-reported hypertension (based on date of diagnosis and use of medication) over an 11- to 18-year follow-up.^75,81^

Three articles examined CVD morbidity (fatal and non-fatal MI, CHD, or CVD) collected from national registries, medical records, or death certificates.^38,86,87^ Follow-up duration for CVD morbidity ranged from 13 to 22 years.

No articles examined CVD mortality.

##### Synthesis of the evidence

Across this small body of evidence, there was substantial variability in study design and outcomes examined. Three PCS measured CVD morbidity, and all found non-significant relationships between substituting processed red meat with unprocessed red meat and risk of CVD morbidity.^38,86,87^ One of those studies did show a trend toward a beneficial relationship substituting processed red meat with unprocessed red meat.^87^ Two additional PCS and the RCT examined blood pressure and showed mixed findings. The RCT and 1 PCS showed a beneficial relationship between unprocessed red meat and blood pressure^70^ or hypertension^81^ compared to processed red meat, while the second PCS found no relationship with hypertension.^75^ The trial also measured blood lipids and found no difference between unprocessed and processed red meat and LDL-C, HDL-C, or triglyceride levels.

Due to the small amount of evidence available for any outcome and the variability in findings across studies, no conclusion could be drawn on unprocessed red meat compared to processed red meat on risk of cardiovascular disease. No conclusion could be drawn on unprocessed white meat compared to processed white meat because there was no evidence.

##### Conclusion statements and grades

The Committee was not able to develop conclusion statements to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence comparing processed meat with unprocessed meat by adults and older adults (Table 24). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias.

Table 24 Conclusion statements and grades for comparing processed meat with unprocessed meat in adults and older adults and risk of cardiovascular disease

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of processed red meat compared to unprocessed red meat by adults and older adults and risk of cardiovascular disease because there is not enough evidence available. | A conclusion statement cannot be drawn about the relationship between consumption of processed white meat compared to unprocessed white meat by adults and older adults and risk of cardiovascular disease because there is no evidence available.
Grade | Grade Not Assignable | Grade Not Assignable
Body of Evidence | 6 articles: 1 RCT, 5 PCS | 0 articles
Rationale | There was not enough evidence for any outcome to allow synthesis. | There was no evidence available examining this relationship in adults and older adults.

#### Articles not included in evidence synthesis

Three RCTs on meat or other animal sources of saturated fat were not included in any of the above synthesis categories due the unique food sources examined in each (Appendix 4)

Rubio et al^76^ enrolled a generally healthy Spanish sample in a crossover RCT and compared the effects of two types of lean, red meat (lean veal and lean pork) on blood lipids over 6 weeks. They found no between-condition differences in LDL-C, HDL-C, or triglycerides.

Sánchez-Muniz et al^77^ enrolled a sample of Spanish adults with overweight or obesity in a crossover RCT and compared the effects of conventional red meat to walnut-enriched red meat on blood lipids. They looked at genetic modification of this relationship, specifically how it was modified by risk allele status. There were no between-condition differences in LDL-C or HDL-C modified by risk allele status, though triglyceride levels and blood pressure showed differences depending on risk allele.

Liu et al^65^ enrolled a sample of generally healthy Chinese adults examined the effect of lard compared to a lard plus soybean blend oil compared to soybean oil consumption over 12 weeks on blood lipids and blood pressure. They found no between-group differences for blood lipids, but systolic blood pressure decreased more in the blend oil and soybean oil groups, with the greatest decrease in the blend oil group, and diastolic blood pressure increased in the lard group only.

As noted above, though these studies were relevant for answering this research question, the unique food sources examined prevented them from being synthesized with any other studies examining meat or other animal sources of saturated fat.

### Meat sources of saturated fat compared to plant sources of saturated fat

#### Description of the evidence

No articles met inclusion criteria and examined the relationship between meat sources of saturated fat (e.g., red meat, white meat, processed meat) compared to plant sources of saturated fat (e.g., palm oil, coconut oil, cocoa butter) consumed by adults and older adults and risk of cardiovascular disease.

#### Conclusion statement and grade

The Committee was not able to develop a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on the lack of evidence to review meat sources of saturated fat compared to plant sources of saturated fat by adults and older adults (Table 25).

Table 25 Conclusion statement and grade for meat sources of saturated fat compared to plant sources of saturated fat in adults and older adults and risk of cardiovascular disease

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of meat sources of saturated fat compared to plant sources of saturated fat by adults and older adults and risk of cardiovascular disease because there is no evidence available.
Grade | Grade Not Assignable
Body of Evidence | 0 articles
Rationale | There was no evidence available examining this relationship in adults and older adults.

### Plant sources of saturated fat

The body of evidence examining plant sources higher in saturated fat consumed by adults and older adults included 16 articles.^8,90–104^ All were RCT (14 crossover,^8,90–96,98,100–104^ 2 parallel^97,99^).

The intervention was consumption of a plant source higher in saturated fat (e.g., palm oil, coconut oil, cocoa butter). The evidence assessing plant sources higher in saturated fat consumed by adults and older adults was categorized based on 3 comparators with available evidence: a food source of monounsaturated and/or polyunsaturated fat, a food source of carbohydrate and/or protein and a different food source of saturated fat. There was no evidence that compared to a similar food source with different amounts of saturated fat. The Committee synthesized the evidence according to the following prioritized intervention/exposure and comparator relationships: plant sources higher in saturated fat compared to vegetable oils higher in unsaturated fat; palm olein compared to vegetable oils higher in unsaturated fat; plant sources higher in saturated fat compared to food sources of carbohydrate or protein; and plant sources higher in saturated fat compared to a different food source of saturated fat. Some articles contributed data to more than one category.

#### Plant sources higher in saturated fat compared to vegetable oils higher in unsaturated fat

##### Description of the evidence

Nine articles examined the effect of plant sources higher in saturated fat compared to vegetable oils higher in unsaturated fat by adults and older adults and risk of CVD: 8 crossover RCT^8,90,91,95,96,98,100,103^; 1 parallel RCT.^99^ Evidence from plant sources higher in saturated fat compared to vegetable oils higher in unsaturated fat in adults and older adults and risk of cardiovascular disease is summarized in Table 78. Risk of bias assessments for each article are summarized in Table 79.

###### Population

Mean baseline age ranged from 23 to 55 years. Two articles enrolled 80% or more females^96,103^; 2 articles did not report sex^90,100^; all other articles had relatively even distribution of male and female enrollment. The analytic sample size ranged from 23^98^ to 67.^91^

Articles included in this body of evidence were conducted in the following countries:

- United States: 3 articles^90,95,98^
- Malaysia: 2 articles^96,103^
- Australia: 1 article^100^
- China: 1 article^91^
- New Zealand: 1 article^8^
- Sweden: 1 article^99^

Two articles were conducted in exclusively or predominantly Asian samples,^8,96^ including 1 article conducted in exclusively Pacific Islanders,^8^ and another in a predominantly Malaysian sample^96^; 1 article was conducted in a predominantly White sample.^98^ Six articles did not report data on race and/or ethnicity.^90,91,95,99,100,103^

None of the studies reported socioeconomic position of the participants.

Two articles exclusively enrolled participants with overweight or obesity,^95,99^ and one study exclusively enrolled participants with elevated LDL cholesterol.^98^ All other articles enrolled participants who were generally healthy and without chronic disease.

###### Intervention and comparator

The intervention of interest was plant sources higher in saturated fat. Two articles examined coconut oil,^8,98^ 3 articles examined cocoa butter,^91,96,100^ 3 articles examined palm oil,^90,99,103^ and 1 article examined chocolate.^95^ Test oils were incorporated into meals or snacks provided by study investigators in most of the studies.^8,90,91,96,98–100,103^ One study provided chocolate and almonds as a snack,^95^ and another study provided the test foods, including butter, coconut oil, and safflower oil, to incorporate into their meals at home while also providing specially baked bread that included the test oils.^8^

Comparators of interest included food sources of monounsaturated and polyunsaturated fatty acids:

- Olive oil: 3 articles^91,96,100^
- 80:20 blend of high-oleic soybean oil and fully hydrogenated soybean oil: 1 article^90^
- Almonds: 1 article^95^
- Corn oil: 1 article^98^
- High-oleic soybean oil: 1 article^90^
- High-oleic palm olein: 1 article^103^
- Safflower oil: 1 article^8^
- Soybean oil: 1 article^90^
- Sunflower oil: 1 article^99^

Two studies compared coconut oil with food sources of polyunsaturated fat such as safflower oil^8^ and corn oil.^98^ Three studies compared cocoa butter with food source of monounsaturated fat such as olive oil.^91,96,100^ One study compared chocolate with food source of monosaturated fat such as almonds.^95^ Three studies compared palm oil with food sources of monosaturated fat, including high-oleic soybean oil,^90^ 80:20 blend of high-oleic soybean oil and fully hydrogenated soybean oil,^90^ high oleic palm olein,^103^ and 2 studies compared palm oil with food sources of polyunsaturated fat, including soybean oil,^90^ and sunflower oil.^99^

Intervention duration varied from 4 weeks^90,91,95,96,98,100^ to 8 weeks.^99^ Two-thirds of studies were controlled feeding trials.^90,91,95,96,100,103^ All studies reported high adherence to prescribed diets.

###### Outcome

All studies measured fasting blood lipids at baseline and at the end of the intervention period. Seven articles measured blood pressure, with 6 measuring at baseline and after each dietary period^90,91,95,98–100^ and 1 article measuring biweekly.^96^

##### Synthesis of the evidence

Synthesis focused on blood lipids and blood pressure due to the lack of data on CVD morbidity and mortality.

###### LDL-C and blood pressure

Among the 10 analyses on LDL cholesterol, most analyses (7 analyses) reported that LDL cholesterol level was significantly higher in plant sources higher in saturated fat compared to plant sources higher in unsaturated fat.^8,90,95,96,99,103^ Three analyses reported null effects, with 2 analyses that tended to show higher LDL cholesterol with consumption of the plant sources higher in saturated fat (coconut oil^98^ or cocoa butter^100^) compared to corn oil^98^ and olive oil^100^ and 1 analysis reporting null effects of cocoa butter, compared to olive oil, on LDL cholesterol.^91^ Overall, findings suggest a beneficial effect of replacing plant sources higher in saturated fat with vegetable oils higher in unsaturated fat on LDL cholesterol.

All 9 analyses on blood pressure reported null effects of plant sources higher in saturated fat, compared to a vegetable source higher in unsaturated fat.^90,91,95,96,98–100^ Among the null findings, 2 analyses reported that systolic blood pressure tended to be higher after consumption of cocoa butter, compared to olive oil,^100^ and after consumption of chocolate, compared to almonds.^95^ Overall, findings suggest no effect of replacing plant sources higher in saturated fat with vegetable oils higher in unsaturated fat on systolic and diastolic blood pressure.

###### HDL-C and triglycerides

Studies reported mixed findings on HDL cholesterol. Six analyses^91,95,96,98–100^ reported null effects of plant sources higher in saturated fat, compared to vegetable oils higher in unsaturated fat, on HDL cholesterol, with 1 reporting a tendency of higher HDL cholesterol with chocolate consumption, compared to almonds.^95^ The 4 analyses that reported significant effects had mixed findings. Three analyses reported that HDL cholesterol was significantly higher in coconut oil compared to safflower oil,^8^ or in palm oil compared to high-oleic soybean oil (HOSBO), or compared to 80:20 blend of HOSBO and fully hydrogenated soybean oil (FHSBO)^90^; 1 analysis reported a significantly lower HDL cholesterol with consumption of palm stearin compared to high oleic palm olein.^103^ Studies reported an increase in HDL cholesterol with an increase in LDL cholesterol, which was observed in 4 analyses.^8,90,95^ Overall, findings were inconsistent in significance and in direction of effect to draw a conclusion statement on HDL cholesterol.

Studies reported mixed findings on triglycerides. Although 10 analyses reported null effects of plant sources higher in saturated fat, compared to various plant sources higher in unsaturated fat, 3 analyses showed that triglycerides tended to be lower in the cocoa butter group compared to olive oil,^100^ lower in palm oil and palm kernel oil compared to high-oleic soybean oil^90^ or compared to HOSBO+FHSBO^90^; 1 analysis reported that triglycerides tended to be higher in the palm oil group compared to soybean oil.^90^ One analysis reported a significant effect, with higher triglycerides with consumption of palm stearin, compared to high oleic palm olein.^103^ Overall, findings were inconsistent in direction of effects to draw a conclusion statement on triglycerides.

##### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on plant sources higher in saturated fat compared to vegetable oils higher in unsaturated fat by adults and older adults (Table 26).

Table 26 Conclusion statement and grade for replacing plant sources higher in saturated fat with vegetable oils higher in unsaturated fat in adults and older adults and risk of cardiovascular disease

Conclusion Statement | Replacing plant sources higher in saturated fat, including coconut oil, cocoa butter, and palm oil, with vegetable oils higher in unsaturated fat, by adults and older adults decreases LDL-C and has no effect on blood pressure. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 9 articles: all RCT (11 comparisons)
Consistency | Few concerns with consistency. Most studies showed an increase in LDL cholesterol with plant sources higher in saturated fat.
Precision | Some concerns with precision due to few studies.
Risk of bias | Some concerns with risk of bias, particularly due to randomization and selection of reported result.
Directness | Few concerns with directness due to most conducting controlled feeding trials.
Generalizability | Substantial concerns due to limited diversity in race and/or ethnicity and socioeconomic position. Few studies reported race and/or ethnicity and socioeconomic position. One third of studies were conducted in the United States.

###### Assessment of the evidence

The body of evidence was assessed for the following elements when grading the strength of the evidence. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, because several studies reported null findings, publication bias may not be a major concern.

###### Consistency

There were few concerns with consistency. Findings were consistent across the body of evidence for replacing plant sources higher in saturated fat with vegetable oils higher in unsaturated fat on LDL cholesterol and blood pressure, with most studies finding higher LDL cholesterol and no effect on blood pressure with consumption of plant sources higher in saturated fat. These findings were noted irrespective of the different comparators including safflower oil, olive oil, almonds, high oleic soybean oil, and high oleic palm olein.

###### Precision

There were few concerns with precision beyond the relatively small number of studies (N=9), with nearly half the (~44%) studies being sufficiently powered. Included studies also had relatively small sample sizes, ranging from 23 to 67.

###### Risk of bias

There are some concerns with risk of bias primarily due to randomization process and selection of reported results. Two-thirds of studies did not provide adequate information about the randomization process, and two-thirds did not have a pre-specified analysis plan.

###### Directness

There were few concerns with directness. Most of the studies were controlled feeding trials designed to directly address the research question of interest.

###### Generalizability

None of the studies reported socioeconomic position and only one-third of studies reported data on race and/or ethnicity, which had limited diversity, limiting the ability to determine generalizability across racial and/or ethnic groups. Only one-third of studies were conducted in the United States, limiting generalizability to the broader U.S. population.

#### Palm olein compared to vegetable oils higher in unsaturated fat

##### Description of the evidence

Six articles examined the effect of palm olein compared to vegetable oils higher in unsaturated fat in adults and older adults and CVD intermediate outcomes: 5 crossover RCTs^91,94,96,100,101^; 1 parallel RCT.^97^ Evidence comparing palm olein to vegetable oils higher in unsaturated fat and CVD intermediate outcomes is summarized in Table 80. Risk of bias assessments for each article are summarized in Table 81.

###### Population

Mean baseline age ranged from 23^91^ to 40 years^101^ in most studies, except 1 article that included participants with a mean age of 64 years.^97^ One article enrolled 92% female,^97^ 1 article enrolled 85% female,^96^ and 1 article did not report sex^100^; all other articles had relatively even distribution of male and female enrollment. The analytic sample size ranged from 34^94^ to 145^97^; 2 articles had analytic sample sizes of 100 or greater.^97,101^

Articles included in this body of evidence were conducted in the following countries:

- China: 2 articles^91,101^
- Malaysia: 2 articles^94,96^
- Australia: 1 article^100^
- Colombia: 1 article^97^

One article was conducted in a predominantly Malaysian sample.^96^ All remaining articles did not report data on race and/or ethnicity. None of the studies reported socioeconomic position.

All articles enrolled participants who were generally healthy and without chronic disease.

###### Intervention and comparator

The intervention of interest was palm olein^91,96,100,101^ in 4 articles, palm olein-based mayonnaise in 1 article^94^ or hybrid palm oil in 1 article.^97^ Palm olein is an industrial oil that is derived from palm oil with lower melting points, higher oleic acid content, lower saturated fat content than palm oil.^91,97,101^ All studies incorporated the test oils into meals or snacks.91,94,96,97,100,101

Comparators of interest included vegetable oils higher in unsaturated fat:

- Olive oil: 5 articles^91,96,97,100,101^
- Soybean oil-based mayonnaise: 1 article^94^

Four articles compared palm olein to olive oil,^91,96,100,101^ 1 article compared hybrid palm oil to olive oil,^97^ and 1 article compared palm olein-based mayonnaise to soybean oil-based mayonnaise.^94^

Intervention duration lasted from 4 weeks^91,94,96,100^ to 3 months.^97^ Five articles were controlled feeding trials, all of which reported high adherence to prescribed diets.^91,94,96,100,101^ One article was not a controlled feeding trial and did not report adherence.^97^

###### Outcomes

All articles measured fasting blood lipids at baseline and after each dietary period. ^91,94,96,97,100,101^ Three articles measured blood pressure at baseline and after each dietary period.^91,96,100^

##### Synthesis of the evidence

Synthesis focused on blood lipids due to the lack of data on blood pressure, CVD morbidity and mortality.

###### Blood lipids

Among the 6 analyses on blood lipids, 5 analyses reported null effects of hybrid palm oil or palm olein, compared to olive oil, on LDL cholesterol.^91,96,97,100,101^ One of these analyses reported a tendency for higher LDL cholesterol with palm olein, compared to olive oil.^100^ Another study reported a statistically significantly higher LDL cholesterol with palm olein-based mayonnaise, compared to soybean oil-based mayonnaise.^94^ Five analyses reported null effects of hybrid palm oil or palm olein, compared to olive oil, on HDL cholesterol. One study reported a statistically significantly higher HDL cholesterol with palm olein-based mayonnaise, compared to soybean oil-based mayonnaise.^94^ Studies report an increase in HDL cholesterol with an increase in LDL cholesterol, which was observed in 1 study.^94^ Five analyses reported null effects of hybrid palm oil, palm olein, or palm olein-based mayonnaise, compared to olive oil or soybean oil-based mayonnaise on triglycerides.^94,96,97,100,101^ One of these studies reported a tendency for higher triglycerides with palm olein, compared to olive oil.^100^ Another study reported statistically significantly lower triglycerides with palm olein, compared to olive oil.^91^ Overall, findings suggest no effect of replacing palm olein with vegetable oils higher in unsaturated fat on blood lipids.

##### Conclusion statement and grade

The Committee developed a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on palm olein compared to vegetable oils higher in unsaturated fat by adults and older adults (Table 27).

Table 27 Conclusion statement and grade for replacing palm olein with vegetable oils higher in unsaturated fat in adults and older adults and risk of cardiovascular disease

Conclusion Statement | Replacing palm olein with vegetable oils higher in unsaturated fat by adults and older adults may not affect blood lipids. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 6 articles: all RCT (6 comparisons)
Consistency | Some concerns with consistency. Most studies reported null findings on blood lipids.
Precision | Some concerns with precision due to few studies.
Risk of bias | Some concerns with risk of bias, particularly randomization and selection of reported result.
Directness | Few concerns with directness due to most conducting controlled feeding trials.
Generalizability | Substantial concerns due to limited diversity in race and/or ethnicity and socioeconomic position. Few studies reported race and/or ethnicity and socioeconomic position. No studies were conducted in the United States.

###### Assessment of the evidence

The body of evidence was assessed for the following elements when grading the strength of the evidence. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, because several studies reported null findings, publication bias may not be a major concern.

###### Consistency

There were some concerns with consistency. Findings were largely consistent across the body of evidence for replacing palm olein with vegetable oils higher in unsaturated fat on blood lipids, with most studies reporting no effect on blood lipids with consumption of palm olein compared to either olive oil or soybean oil-based mayonnaise. A small number of studies showed higher LDL cholesterol, higher HDL cholesterol, and higher and lower triglycerides.

###### Precision

There were some concerns with precision beyond the relatively small number of studies (N=6), with one study being sufficiently powered. Most of the studies also had relatively small sample sizes, ranging from 34 to 145.

###### Risk of bias

There are some concerns with risk of bias primarily due to randomization process, missing outcome data, and selection of reported results. Most of the studies did not provide adequate information about the randomization process, one-third of studies had high rates of missing outcome data and did not compare between included and excluded participants, and no studies had a pre-specified analysis plan.

###### Directness

There were few concerns with directness. Most of the studies were controlled feeding trials designed to directly address the research question of interest.

###### Generalizability

None of the studies reported socioeconomic position and only one study reported data on race and/or ethnicity, which had limited diversity, limiting the ability to determine generalizability across racial and/or ethnic groups. No studies were conducted in the United States, limiting generalizability to the broader U.S. population.

#### Plant sources higher in saturated fat compared to a different food source of saturated fat

##### Description of the evidence

Six articles examined the effect of plant sources higher in saturated fat compared to a different food source of saturated fat by adults and older adults and risk of cardiovascular disease.^8,91,96,100,102,104^ All studies were crossover RCT. Evidence from plant sources higher in saturated fat compared to a different source of fat in adults and older adults and risk of cardiovascular disease is summarized in Table 82. Risk of bias assessments for each article are summarized in Table 83.

###### Population

Participants mean baseline age ranged from 23^91^ to 35 years^8^ in most studies, while 1 study included participants with an average of 62 years.^104^ One article reported approximately 66% were female,^102^ another reported 85% female,^96^ and 1 study did not report sex^100^; all other articles had relatively even distribution of male and female enrollment.^8,91,104^ The analytic sample size ranged from 30^102^ to 67.^91^

Articles included in this body of evidence were conducted in the following countries:

- Malaysia: 2 articles^96,102^
- Australia: 1 article^100^
- China: 1 article^91^
- Netherlands: 1 article^104^
- New Zealand: 1 article^8^

In the 2 articles that reported race and/or ethnicity, one article reported 100% Pacific Islanders,^8^ and another reported predominantly Malay.^96^ None of the studies reported socioeconomic position.

All articles enrolled participants who were generally healthy and without chronic disease.

###### Intervention and comparator

The intervention of interest was plant sources higher in saturated fat. Three articles examined cocoa butter,^91,96,100^ 1 examined coconut oil,^8^ 1 examined palm olein,^102^ and 1 examined a palmitic acid-rich blend.^104^ Test oils were incorporated into meals and snacks in all studies, with 1 study providing test fats, including butter, coconut oil, and safflower oil, in addition to the baked breads that incorporated these oils or fats.^8^

Comparator of interest was a different food source of saturated fat:

- Palm olein: 3 articles^91,96,100^
- Butter: 1 article^8^
- Stearic acid-rich blend: 1 article^104^
- Interesterified soybean oil: 1 article^102^

Three articles compared cocoa butter to palm olein^91,96,100^; 1 article compared coconut oil to butter,^8^ 1 article compared palmitic acid-rich blend (90% palm oil, 10% high-oleic sunflower oil) to stearic acid-rich blend (92% allanblackia oil, 8% sunflower oil)^104^ and 1 article compared palm olein to interesterified soybean oil.^102^

Most intervention duration was 4 weeks,^91,96,100,102,104^ and one study had a duration of 6 weeks.^8^ All but 1 study were controlled feeding trials.^91,96,100,102,104^ All studies reported high adherence to the dietary interventions.

###### Outcome

All studies measured fasting blood lipids at baseline and after each dietary period. Three studies measured blood pressure at baseline and after each dietary period.^91,96,100,104^

##### Synthesis of the evidence

Among the 6 analyses that examined LDL cholesterol, 4 analyses reported null effects of cocoa butter or palm olein, compared to palm olein and interesterified soybean oil, respectively.^91,96,100,102^ One of these studies reported that LDL cholesterol tended to decrease with cocoa butter, compared to palm olein.^100^ Two analyses reported statistically significant effects, 1 of which reported higher LDL cholesterol after consumption of 90% palm oil and 10% high-oleic sunflower oil compared to 92% allanblackia oil and 8% sunflower oil,^104^ and another which reported statistically significantly lower LDL cholesterol after consumption of coconut oil, compared to butter.^8^ Among the 6 analyses that examined HDL cholesterol, 3 analyses reported null effects of coconut oil or cocoa butter, compared to butter or palm olein, respectively, on HDL cholesterol, and 3 analyses reported statistically significant effects, with mixed findings. Two studies reported higher HDL cholesterol with 90% palm oil or palm olein, compared to 92% allanblackia oil and 8% sunflower oil^104^ or interesterified soybean oil,^102^ respectively. Studies report an increase in HDL cholesterol with an increase in LDL cholesterol, which was observed in 1 study.^104^ One reported lower HDL cholesterol with cocoa butter compared to palm olein.^96^ Overall, findings were inconsistent in significance and in direction of effects to draw a conclusion statement on the effect of plant sources of saturated fat compared to a different food source of saturated fat in adults and older adults on LDL and HDL cholesterol.

All 6 analyses that examined triglycerides reported null effects of coconut oil, cocoa butter, 90% palm oil and 10% high-oleic sunflower oil, and palm olein, compared to another food sources of saturated fat, on triglycerides.^8,91,96,100,102,104^ However, 1 study reported a tendency of lower triglycerides with consumption of cocoa butter compared to palm olein.^100^ The intervention-comparator pairs were too heterogeneous to draw a conclusion statement on plant sources of saturated fat compared to a different food source of saturated fat in adults and older adults on triglycerides despite consistencies in findings.

All 4 analyses that examined blood pressure reported null effects of cocoa butter^91,96,100^ and 90% palm oil and 10% high-oleic sunflower oil,^104^ compared to palm olein or 92% allanblackia oil and 8% sunflower oil, respectively. There were too few studies on blood pressure to draw a conclusion on plant sources of saturated fat compared to a different food source of saturated fat in adults and older adults on blood pressure.

##### Conclusion statement and grade

The Committee was not able to develop a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence on plant sources higher in saturated fat compared to a different food source of saturated fat by adults and older adults (Table 28). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, because several studies reported null findings, publication bias may not be a major concern.

Table 28 Conclusion statement and grade for plant sources higher in saturated fat compared to a different food source of saturated fat in adults and older adults and risk of cardiovascular disease

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of plant sources higher in saturated fat, compared to a different food source of saturated fat (including dairy, meat, or another plant source of saturated fat), by adults and older adults and risk of cardiovascular disease because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 6 articles: all RCT
Rationale | Substantial concerns with too few studies and inconsistencies in significance of findings and direction of effects of significant results.

#### Plant sources higher in saturated fat compared to food sources of carbohydrate or protein

##### Description of the evidence

Two articles examined the effect of plant sources higher in saturated fat compared to food sources of carbohydrate or protein in adults and older adults on CVD intermediate outcomes: all were crossover RCTs.^92,93^ Evidence comparing plant sources higher in saturated fat to food sources of carbohydrate or protein is summarized in Table 84. Risk of bias assessments for each article are summarized in Table 85.

###### Population

Mean baseline age ranged from 21^92^ to 43 years.^93^ Both articles had relatively even distribution of male and female enrollment. The analytic sample size ranged from 32^92^ to 60.^93^

Articles included in this body of evidence were conducted in the following countries:

- Sri Lanka: 1 article^93^
- Thailand: 1 article^92^

Neither article reported data on race and/or ethnicity and socioeconomic position. Both articles enrolled participants who were generally healthy and without chronic disease.

###### Intervention and comparator

The intervention and comparator of interest were coconut oil compared to carboxymethylcellulose,^92^ and coconut milk porridge compared to soya milk porridge.^93^ The coconut milk and soy milk porridge were prepared using commercially available coconut milk or soya milk powder.^93^ The coconut oil compared to carboxymethylcellulose did not specify how the coconut oil was consumed.^92^

Intervention duration was 8 weeks in both studies.^92,93^ Neither study was controlled feeding trials and neither reported adherence to dietary interventions.

###### Outcome

Both studies measured fasting blood lipids at baseline and after each dietary period. One study measured blood pressure at baseline and after each dietary period.^92^

##### Synthesis of the evidence

Both studies reported null effects of coconut oil or coconut milk porridge, compared to carboxymethylcellulose or soya milk porridge, respectively on LDL cholesterol. Both studies reported significantly higher HDL cholesterol with coconut oil or coconut milk porridge consumption. There were no effects on triglycerides and blood pressure in one study.^92^

Due to the small amount of evidence available, no conclusion could be drawn on the effect of plant sources higher in saturated fat compared to food sources of carbohydrate or protein in adults and older adults on blood lipids or blood pressure.

##### Conclusion statement and grade

The Committee was not able to develop a conclusion statement to answer the question: “What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease?” based on their review of evidence comparing plant sources higher in saturated fat compared to food sources of carbohydrate or protein by adults and older adults (Table 29). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, because several studies reported null findings, publication bias may not be a major concern.

Table 29 Conclusion statement and grade for plant sources higher in saturated fat compared to food sources of carbohydrate or protein in adults and older adults and risk of cardiovascular disease

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of plant sources higher in saturated fat, compared to food sources of carbohydrate or protein, by adults and older adults and risk of cardiovascular disease because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 2 articles: 2 RCT
Rationale | There was not enough evidence for any outcome to allow synthesis.