# Plain language summary

### What is the question?

The question is: What is the relationship between food sources of saturated fat consumed and risk of cardiovascular disease? The population of interest included children and adolescents, and adults and older adults.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a new systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team.

### What is the answer to the question?

#### Children and adolescents

- A conclusion statement cannot be drawn about dairy sources of saturated fat and different comparators consumed by children and adolescents and the relationship with blood lipids or blood pressure because there is not enough evidence available. Comparators considered included similar food sources with different amounts of total fat; food sources of unsaturated fat, carbohydrate, or protein; or a different food source of saturated fat.
- A conclusion statement cannot be drawn about meat sources of saturated fat (including red meat, processed meat, and white meat) and different comparators consumed by children and adolescents and the relationship with blood lipids or blood pressure because there is no evidence available. Comparators considered included similar food sources with different amounts of total fat; food sources of unsaturated fat, carbohydrate, or protein; or a different food source of saturated fat.
- A conclusion statement cannot be drawn about plant sources higher in saturated fat (such as palm oil, coconut oil, or cocoa butter) and different comparators consumed by children and adolescents and the relationship with blood lipids or blood pressure because there is no evidence available. Comparators considered included similar food sources with different amounts of total fat; food sources of unsaturated fat, carbohydrate, or protein; or a different food source of saturated fat.

#### Adults and older adults

##### Dairy sources of saturated fat

- Substituting higher-fat dairy with lower-fat dairy by adults and older adults is not associated with a difference in risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as limited.
- A conclusion statement cannot be drawn about the relationship between higher-fat dairy consumption, compared to their lower-fat versions, by adults and older adults and blood lipids, blood pressure and cardiovascular disease mortality because there is not enough evidence available.
- Substituting dairy with food sources of unsaturated fatty acids by adults and older adults may be associated with a lower risk of cardiovascular disease. This conclusion statement is based on evidence graded as limited.
- Replacing butter with plant-based oils and spreads, with predominantly unsaturated fatty acids, by adults and older adults decreases LDL-C levels but does not affect HDL-C or triglyceride levels. This conclusion statement is based on evidence graded as strong.
- Substituting butter with plant-based oils and spreads, with predominantly unsaturated fatty acids, by adults and older adults may be associated with a decreased risk of cardiovascular disease morbidity and mortality. This conclusion statement is based on evidence graded as limited.
- Substituting or replacing one form of dairy (including milk, yogurt, cheese, butter and buttermilk) with another form of dairy by adults and older adults is not associated with a difference in risk of cardiovascular disease. This conclusion statement is based on evidence graded as moderate.
- A conclusion statement cannot be drawn about the relationship between consumption of dairy compared to food sources of carbohydrates and protein by adults and older adults and risk of cardiovascular disease because of substantial concerns with consistency in the body of evidence.

##### Dairy sources of saturated fat compared to meat sources of saturated fat

- Substituting processed meat and red meat with dairy by adults and older adults is associated with a lower risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
- A conclusion statement cannot be drawn about the relationship between replacing dairy with meat consumption by adults and older adults and blood lipids, blood pressure, and cardiovascular disease mortality because there is not enough evidence available.

##### Meat sources of saturated fat

- Substituting processed or unprocessed red meat with plant sources of protein (such as beans, peas, lentils, nuts, seeds, or soy) by adults and older adults is associated with lower risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
- Substituting processed or unprocessed red meat with whole grains by adults and older adults is associated with lower risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
- Substituting processed or unprocessed red meat with vegetables by adults and older adults is associated with lower risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
- Substituting processed or unprocessed red meat with fish or seafood by adults and older adults may not be associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as limited.
- Substituting processed or unprocessed red meat with white meat by adults and older adults is not associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
- Replacing consumption of lean, unprocessed red meat with lean, unprocessed white meat by adults and older adults may not affect blood lipids or blood pressure. This conclusion statement is based on evidence graded as limited.
- Substituting processed or unprocessed red meat with eggs by adults and older adults is not associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
- Substituting white meat with plant-based foods by adults and older adults is not associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
- Substituting white meat with fish or seafood by adults and older adults is not associated with risk of cardiovascular disease morbidity. This conclusion statement is based on evidence graded as moderate.
- A conclusion statement cannot be drawn about the effects of unprocessed meat consumption compared to plant-based foods on blood lipids or blood pressure in adults and older adults because of substantial concerns with consistency of the comparator, directness, risk of bias, and precision in the body of evidence.
- A conclusion statement cannot be drawn about the relationship between consumption of red meat with different amounts of saturated fat by adults and older adults and risk of cardiovascular disease because there is not enough evidence available.
- A conclusion statement cannot be drawn about the relationship between consumption of white meat with different amounts of saturated fat by adults and older adults and risk of cardiovascular disease because there is no evidence available.
- A conclusion statement cannot be drawn about the relationship between consumption of processed red meat compared to unprocessed red meat by adults and older adults and risk of cardiovascular disease because there is not enough evidence available.
- A conclusion statement cannot be drawn about the relationship between consumption of processed white meat compared to unprocessed white meat by adults and older adults and risk of cardiovascular disease because there is no evidence available.

##### Meat sources of saturated fat compared to plant sources of saturated fat

- A conclusion statement cannot be drawn about the relationship between consumption of meat sources of saturated fat compared to plant sources of saturated fat by adults and older adults and risk of cardiovascular disease because there is no evidence available.

##### Plant sources of saturated fat

- Replacing plant sources higher in saturated fat, including coconut oil, cocoa butter, and palm oil, with vegetable oils higher in unsaturated fat, by adults and older adults decreases LDL-C and has no effect on blood pressure. This conclusion statement is based on evidence graded as moderate.
- Replacing palm olein with vegetable oils higher in unsaturated fat by adults and older adults may not affect blood lipids. This conclusion statement is based on evidence graded as limited.
- A conclusion statement cannot be drawn about the relationship between consumption of plant sources higher in saturated fat, compared to food sources of carbohydrate or protein, by adults and older adults and risk of cardiovascular disease because there is not enough evidence available.
- A conclusion statement cannot be drawn about the relationship between consumption of plant sources higher in saturated fat, compared to a different food source of saturated fat (including dairy, meat, or another plant source of saturated fat), by adults and older adults and risk of cardiovascular disease because there is not enough evidence available.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 1990 and January 2024.