# Appendix 4 Articles not included in evidence synthesis for meat sources of saturated

Some articles examining meat sources of saturated fat were not included in evidence synthesis (Table A 6). Risk of bias assessments for these articles are summarized in Table A 7.

Table A 6 Evidence examining the relationship between meat sources of saturated fat consumed in adults and older adults and risk of cardiovascular disease that were not included in evidence synthesis^a^

Study and Participant Characteristics | Intervention/Exposure and Comparator | Results | Methodological Considerations
Liu, 2023^65^; RCT-parallel, China; Analytic N = 334; Adequately powered:; Yes; Study aims: To assess the effects of lard plus soybean oil on liver function markers in healthy participants; Participant characteristics:; - Age: 33.1y; 18-63y; - Female: 60%; - Race and/or ethnicity: NR but likely majority Asian; - SEP: NR; - BMI: 24 (4) kg/m^2^; - Health Status: Generally healthy; Excluded <18 or >63y; BMI <16 or >39 kg/m^2^; those on HTN medication; history of CVD, diabetes, or cancer; allergy or intolerance to lard; pregnant or planned pregnancy; particular nutritional habits such as vegetarianism | Intervention: Lard (N=110): 30 g/d (39% SFA, 45% MUFA, 16% PUFA); Comparator: Soybean oil (N=113): 30 g/d (11% SFA, 22% MUFA, 68% PUFA) Blend oil (N=111): 30 g/d of 50% soybean oil and 50% lard (23% SFA, 32% MUFA, 45% PUFA); Duration: 12wk; Compliance: Yes, direct observation of number of missed meals; Outcome assessment methods and timing:; - LDL, HDL, TG, SBP, DBP; - Fasting blood collection and blood pressure measured at baseline, 4wk, 8wk, and 12wk | [underlined: LDL (mmol/L)], Mean (95% CI); Within group: baseline, ∆12wk; Soybean oil: 2.54 (2.44, 2.65), −0.06 (−0.13, 0.01); Blend oil: 2.66 (2.53, 2.79), −0.05 (−0.13, 0.03); Lard: 2.62 (2.50, 2.74), 0.00 (−0.09, 0.08); Between group: ∆12wk; P-interaction=0.532; [underlined: HDL (mmol/L)], Mean (95% CI); Within group: baseline, ∆12wk; Soybean oil: 1.69 (1.62, 1.76), −0.22 (−0.26, −0.18); Blend oil: 1.71 (1.66, 1.76), −0.19 (−0.23, −0.15); Lard: 1.70 (1.63, 1.76), −0.20 (−0.24, −0.17); Between group: ∆12wk; P-interaction=0.760; [underlined: TG (mmol/L)], Mean (95% CI); Within group: baseline, ∆12wk; Soybean oil: 1.09 (0.95, 1.23), −0.11 (−0.20, −0.03); Blend oil: 1.08 (0.97, 1.19), −0.13 (−0.23, −0.03); Lard: 1.14 (1.00, 1.28), −0.09 (−0.22, 0.04); Between group: ∆12wk; P-interaction=0.755; [underlined: SBP (mmHg)], Mean (95% CI); Within group: baseline, ∆12wk; Soybean oil: 115.5 (113.2, 117.8), −3.3 (−5.7, −0.9); Blend oil: 116.9 (114.3, 119.5), −6.0 (−8.6, −3.4); Lard: 115.3 (113.6, 117.1), −1.2 (−3.7, 1.4); Between group: ∆12wk; (mean of every 4wk); P-interaction=0.023; Blend oil vs Lard: P<0.001; Soybean oil vs Lard: P=0.260; [underlined: DBP (mmHg)], Mean (95% CI); Within group: baseline, ∆12wk; Soybean oil: 74.6 (73.0, 76.2), 1.5 (−1.0, 4.0); Blend oil: 75.6 (73.7, 77.5), 0.8 (−1.7, 3.2); Lard: 74.0 (72.5, 75.5), 3.3 (0.9, 5.8); Between group: ∆12wk (mean of every 4wk); P-interaction=0.008; Blend oil vs Lard: P<0.001; Soybean oil vs Lard: P=0.099 | Limitations:; None identified; Funding:; National Natural Science Foundation of China; Key Scientific Research Projects in Shandong Province China; Postdoctoral Science Foundation of Qingdao
Rubio, 2006^76^; RCT-crossover, Spain; Analytic N = 44; Adequately powered:; Yes; Study aims: To compare how lean pork consumption and lean veal consumption, as part of the fat- and cholesterol- controlled diet recommended by the Spanish Society of Arteriosclerosis, affect the lipid profiles of healthy subjects.; Participant characteristics:; - Age: ~23 (3)y; - Female: 50%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: ~21 (1) kg/m^2^; - Health Status: BP at baseline: ~105/69; Excluded those with overweight or obesity, evidence of any systemic disease, taking any medication, total cholesterol >6.2 mmol/L or <3.87 mmol/L, LDL >4.13 mmol/L or <2.06 mmol/L, triglycerides >2.25 mmol/L, HDL <0.9 mmol/L, regular alcohol consumption >20 g/d and/or tobacco consumption >10 cigarettes/d, physical exercise >1000 kcal/wk or energy consumption <1500 kcal/d or <30% of energy in total fat | Intervention: Veal, lean: 150 g/day (6.75g total fat); sirloin or filet; Comparator: Pork, lean: 150 g/day (8.5g total fat); leg, loin, or sirloin; Duration: 6wk each (5wk washout) Compliance: Yes, 100% attendance at programmed visits, blood analyses and nutritional records, 97% ate all main meals; Outcome assessment methods and timing:; - LDL, HDL, TG; - Fasting blood collection at baseline and after each 6wk intervention | [underlined: LDL (mmol/L)], Median (SD); Within group: baseline, 6wk; Veal: 2.82 (0.58), 2.71 (0.47), P=0.052; Pork: 2.81 (0.59), 2.62 (0.55), P<0.001; Between group: % change over 6wk; Veal: −4.1; Pork: −6.5; P=0.294; [underlined: HDL (mmol/L)], Median (SD); Within group: baseline, 6wk; Veal: 1.60 (0.34), 1.58 (0.29), P=0.374; Pork: 1.63 (0.3), 1.59 (0.31), P=0.171; Between group: % change over 6wk; Veal: −1.4; Pork: −2.7; P=0.640; [underlined: TG (mmol/L)], Median (SD); Within group: baseline, 6wk; Veal: 0.77 (0.20), 0.70 (0.19), P=0.012; Pork: 0.73 (0.20), 0.71 (0.21), P=0.280; Between group: % change over 6wk; Veal: −9.8; Pork: −2.9; P=0.181 | Limitations:; - Methods for randomization and concealment not described; - No preregistered protocol; Funding:; Vaquero Foundation
Sánchez-Muniz, 2012^77^; RCT-crossover, Spain; Analytic N = 22 (QQ, N=11; QR+RR, N=11; LL, N=8; LM+MM, N=14); Adequately powered: Yes; Study aims: To compare the effects of consuming walnut-enriched meat products vs low-fat meat on reduced and oxidized glutathione, lipoperoxides, alpha and gamma-tocopherol levels, and paraoxonase, catalase, and superoxide dismutase activities in individuals at high cardiovascular risk carrying different PON-1 192/55 polymorphisms; Participant characteristics:; - Age: 54.8y (men ≥45y, women ≥50y); - Female: 45%; - Race and/or ethnicity: NR; - SEP: NR; - BMI: 29.6 kg/m^2^ (55% with overweight, 45% with obesity); - Health Status: All with HTN; Included men ≥45y; women ≥50y & postmenopausal; BMI 25-<35 kg/m^2^; having ≥1 of the following: elevated total cholesterol, current smoking ≥10 cigarettes/day, or hypertension; frequent meat product consumers (≥5 times/wk) Excluded those with familial hypercholesterolemia IIa and/or type I and II diabetes; use of vitamin or mineral supplements; hormone replacement therapy; regular use of aspirin and medications known to affect lipid absorption or metabolism and any chronic disease (e.g. antidiabetic, antiaggregant drugs); nonfrequent meat products consumption (<5 times/wk) | Intervention: Conventional meat products (Control): four 150g restructured beef steaks and 150g of frankfurter sausages each week; providing 96 kcal, 20.6g PRO, 1.6g fat, 42.1g SFA, 38.0g MUFA, and 19.8g PUFA per 100g of meat; Comparator: Walnut-enriched meat: four 150g restructured walnut paste-enriched beef steaks and 150g of walnut paste-enriched frankfurter sausages each week (all containing 20% walnut paste); providing 209 kcal, 19.5g PRO, 14.5g fat, 11.2g SFA, 13.7g MUFA, and 74.9g PUFA per 100g of meat; Results were provided by paraoxonase-1 (PON-1) 192 and 55 polymorphisms (QQ, QR+RR, LL, LM+MM); Duration: 5wk each (4-6wk washout) Compliance: Yes, based on consumption and serum concentration of γ-tocopherol; Outcome assessment methods and timing:; - LDL, HDL, TG, SBP, DBP; - Fasting blood collection and blood pressure at baseline and after each 5wk period | [underlined: LDL (mg/dL)] by each PON-1 allele, Mean (SD); Within group: baseline, 5wk; Walnut-enriched meat; QQ: 123.7 (31.4), 125.0 (32.2), P=NS; QR+RR: 161.9 (31.4),159.0 (18.5), P=NS; LL: 155.3 (27.2),161.8 (19.1), P=NS; LL+MM: 131.4 (39.1), 126.3 (30.5), P=NS; Conventional meat; QQ: 137.6 (37.0), 133.1 (37.0), P=NS; QR+RR: 169.1 (30.8), 159.3 (23.1), P=NS; LL: 174.8 (35.0), 164.5 (30.6), P=NS; LL+MM: 139.7 (33.2), 134.7 (32.5), P=NS; Between group:; QQ vs QR+RR: P-interaction=0.547; LL vs LL+MM: P-interaction=0.704; [underlined: HDL (mg/dL)] by each PON-1 allele, Mean (SD); Within group: baseline, 5wk; Walnut-enriched meat; QQ: 42.5 (9.8), 40.8 (8.9), P=NS; QR+RR: 51.3 (11.2), 46.3 (9.1), P=NS; LL: 47.4 (6.8), 45.6 (9.7), P=NS; LL+MM: 45.7 (13.4), 41.7 (8.9), P<0.05; Conventional meat; QQ: 44.2 (7.3), 39.5 (5.2), P<0.05; QR+RR: 47.9 (10.9), 43.7 (6.5), P=NS; LL: 48.9 (10.2), 42.1 (5.8), P<0.05; LL+MM: 44.2 (8.2), 40.9 (6.3), P<0.05; Between group:; QQ vs QR+RR: P-interaction=0.531; LL vs LL+MM: P-interaction=0.795; [underlined: TG (mg/dL)] by each PON-1 allele, Mean (SD); Within group: baseline, 5wk; Walnut-enriched meat; QQ: 143.5 (76.3), 158.1 (63.7), P=NS; QR+RR: 152.1 (80.5), 129.5 (49.1), P=NS; LL: 186.8 (70.8),155.3 (58.4), P=NS; LL+MM: 122.2 (70.7), 139.1 (59.5), P=NS; Conventional meat; QQ: 132.8 (63.2), 155.1 (72.1), P=NS; QR+RR: 142.3 (64.5), 122.4 (45.0), P=NS; LL: 155.0 (63.7), 139.3 (72.0), P=NS; LL+MM: 127.8 (62.1), 142.0 (61.4), P=NS; Between group:; QQ vs QR+RR: P-interaction=0.024; LL vs LL+MM: P-interaction=0.031; [underlined: SBP (mmHg)] by each PON-1 allele, Mean (SD); Within group: baseline, 5wk; Walnut-enriched meat; QQ: 138.3 (14.1), 137.8 (15.8), P=NS; QR+RR: 151.1 (28.8), 135.3 (11.1), P=NS; LL: 160.7 (24.5), 139.2 (7.5), P<0.05; LL+MM: 134.6 (15.3), 135.2 (16.2), P=NS; Conventional meat; QQ: 144.2 (20.6), 138.8 (15.9), P=NS; QR+RR: 147.4 (31.8), 142.1 (26.6), P=NS; LL: 158.0 (30.7), 147.6 (27.6), P=NS; LL+MM: 138.6 (20.2), 135.9 (15.6), P=NS; Between group:; QQ vs QR+RR: P-interaction=0.276; LL vs LL+MM: P-interaction=0.033; [underlined: DBP (mmHg)] by each PON-1 allele, Mean (SD); Within group: baseline, 5wk; Walnut-enriched meat; QQ: 89.2 (7.2), 87.7 (10.7), P=NS; QR+RR: 107.9 (34.1), 83.6 (6.5), P<0.05; LL: 114.5 (37.4), 85.2 (10.8), P<0.05; LL+MM: 89.5 (9.1), 85.9 (8.1), P=NS; Conventional meat; QQ: 93.9 (11.5), 82.7 (9.7), P<0.05; QR+RR: 94.2 (18.8), 86.6 (10.0), P=NS; LL: 102.6 (14.0), 86.0 (10.0), P=NS; LL+MM: 89.1 (14.1), 83.9 (7.3), P=NS; Between group:; QQ vs QR+RR: P-interaction=0.149; LL vs LL+MM: P-interaction=0.007 | Limitations:; - Insufficient information on randomization and allocation procedures; - Inadequately powered; - No preregistered data analysis plan; Funding:; Spanish Ministerio de Educación y Ciencia; Consolider-Ingenio 2010

a Abbreviations: AHEI: Alternative Healthy Eating Index; BMI: body mass index; CABG: coronary artery bypass grafting; CHD: coronary heart disease; CHO: carbohydrate; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DBP: diastolic blood pressure; dL: deciliter(s); DM: diabetes mellitus; eq: equivalent; FFQ: food frequency questionnaire; HDL: high-density lipoprotein cholesterol; HTN: hypertension; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); m: meter(s); L: liter(s); LDL: low-density lipoprotein cholesterol; MI: myocardial infarction; mmHg: millimetre of mercury; mmol: millimole(s); mo: month(s); MUFA: monounsaturated fatty acids; NCC: nested case control; NR: not reported; NS: not significant; OR: odds ratio; oz: ounce(s); P: p-value; PCS: prospective cohort study; PUFA: polyunsaturated fatty acids; RCT: randomized controlled trial; RR: risk ratio; SBP: systolic blood pressure; SD: standard deviation; SEM: standard error of the mean; SFA: saturated fatty acids; SEP: socioeconomic position; SSB: sugar-sweetened beverages; svg: serving(s); T2D: type 2 diabetes; TEI: total energy intake; TG: triglycerides; wk: week(s); y: year(s)

Table A 7 Risk of bias for randomized controlled trials examining meat sources of saturated fat consumed in adults and older adults and risk of cardiovascular disease that were not included in evidence synthesis^a^

Article | Randomization | Carryover effects | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Liu, 2023^65^ | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Rubio, 2006^76^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Sánchez-Muniz, 2012^77^ | SOME CONCERNS | LOW | LOW* | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 ) * Deviations from intended interventions (per-protocol)