# Appendix 3 Excluded articles

The following table lists the articles excluded after full-text screening for this systematic review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 5 Articles excluded after full-text screening

| Citation | Rationale
1 | [No authors listed]. Correction of Dairy consumption, systolic blood pressure, and risk of hypertension. Bmj. 2017. 358:j3550. doi:10.1136/bmj.j3550 | Study design; Publication status
2 | [No authors listed]. Increased risk of coronary disease. Nurs Stand. 1993;7(26):14. doi:10.7748/ns.7.26.14.s28 | Study design
3 | Aadland EK, Lavigne C, Graff IE, et al. Lean-seafood intake reduces cardiovascular lipid risk factors in healthy subjects: results from a randomized controlled trial with a crossover design. Am J Clin Nutr. 2015. 102:582-92. doi:10.3945/ajcn.115.112086 | Intervention/Exposure; Comparator
4 | Abbaspour N, Roberts T, Hooshmand S, Kern M, Hong MY. Mixed Nut Consumption May Improve Cardiovascular Disease Risk Factors in Overweight and Obese Adults. Nutrients. Jun 29 2019;11(7)doi:10.3390/nu11071488 | Intervention/Exposure
5 | Abbey M, Clifton P, Kestin M, Belling B, Nestel P. Effect of fish oil on lipoproteins, lecithin:cholesterol acyltransferase, and lipid transfer protein activity in humans. Arteriosclerosis. Jan-Feb 1990;10(1):85-94. doi:10.1161/01.atv.10.1.85 | Intervention/Exposure; Sample size/Power
6 | Abbey M, Nestel PJ. Plasma cholesteryl ester transfer protein activity is increased when trans-elaidic acid is substituted for cis-oleic acid in the diet. Atherosclerosis. 1994. 106:99-107. doi:10.1016/0021-9150(94)90086-8 | Intervention/Exposure; Sample size/Power
7 | Abbott RD, Curb JD, Rodriguez BL, Sharp DS, Burchfiel CM, Yano K. Effect of dietary calcium and milk consumption on risk of thromboembolic stroke in older middle-aged men. The Honolulu Heart Program. Stroke. May 1996;27(5):813-8. doi:10.1161/01.str.27.5.813 | Intervention/Exposure; No confounder adjustment
8 | Abdullah MM, Cyr A, Lépine MC, et al. Common Variants in Cholesterol Synthesis- and Transport-Related Genes Associate with Circulating Cholesterol Responses to Intakes of Conventional Dairy Products in Healthy Individuals. J Nutr. 2016. 146:1008-16. doi:10.3945/jn.115.222208 | Intervention/Exposure
9 | Abdullah MM, Cyr A, Lépine MC, et al. Recommended dairy product intake modulates circulating fatty acid profile in healthy adults: a multi-centre cross-over study. Br J Nutr. 2015. 113:435-44. doi:10.1017/s0007114514003894 | Intervention/Exposure; Comparator
10 | Abdullah MMH, Eck PK, Couture P, et al. The combination of single nucleotide polymorphisms rs6720173 (ABCG5), rs3808607 (CYP7A1), and rs760241 (DHCR7) is associated with differing serum cholesterol responses to dairy consumption. Applied Physiology Nutrition and Metabolism. Oct 2018;43(10):1090-1093. doi:10.1139/apnm-2018-0085 | Comparator
11 | Abou-Zeid NA. New type of Domiati cheese of potential benefit to people with high blood cholesterol. J Dairy Res. Feb 1992;59(1):89-94. doi:10.1017/s0022029900030284 | Study design; Non-human
12 | Acosta S, Johansson A, Drake I. Diet and Lifestyle Factors and Risk of Atherosclerotic Cardiovascular Disease-A Prospective Cohort Study. Nutrients. Oct 27 2021;13(11)doi:10.3390/nu13113822 | Intervention/Exposure
13 | Acosta-Navarro JC, Oki AM, Antoniazzi L, et al. Consumption of animal-based and processed food associated with cardiovascular risk factors and subclinical atherosclerosis biomarkers in men. Revista da Associacao Medica Brasileira. 2019. 65:43-50. doi:10.1590/1806-9282.65.1.43 | Study design; Intervention/Exposure
14 | Adachi H, Hino A. Trends in nutritional intake and serum cholesterol levels over 40 years in Tanushimaru, Japanese men. J Epidemiol. 2005. 15:85-9. doi:10.2188/jea.15.85 | Study design
15 | Adamkova V, Kacer P, Mraz J, et al. The consumption of the carp meat and plasma lipids in secondary prevention in the heart ischemic disease patients. Neuro Endocrinol Lett. 2011;32 Suppl 2:17-20. | Intervention/Exposure; Health status
16 | Adamo M, Labate AM, Ferrulli A, Macri C, Terruzzi I, Luzi L. Effects of hazelnuts and cocoa on vascular reactivity in healthy subjects: a randomised study. Int J Food Sci Nutr. Mar 2018;69(2):223-234. doi:10.1080/09637486.2017.1348492 | Intervention/Exposure
17 | Adams TH, Walzem RL, Smith DR, et al. Hamburger high in total, saturated and trans-fatty acids decreases HDL cholesterol and LDL particle diameter, and increases TAG, in mildly hypercholesterolaemic men. Br J Nutr. 2010. 103:91-8. doi:10.1017/s0007114509991516 | Sample size/Power
18 | Adamsson V, Reumark A, Fredriksson IB, et al. Effects of a healthy Nordic diet on cardiovascular risk factors in hypercholesterolaemic subjects: a randomized controlled trial (NORDIET). J Intern Med. Feb 2011;269(2):150-9. doi:10.1111/j.1365-2796.2010.02290.x | Intervention/Exposure
19 | Adamsson V, Reumark A, Marklund M, Larsson A, Riserus U. Role of a prudent breakfast in improving cardiometabolic risk factors in subjects with hypercholesterolemia: a randomized controlled trial. Clin Nutr. Feb 2015;34(1):20-6. doi:10.1016/j.clnu.2014.04.009 | Intervention/Exposure
20 | Adamsson V, Cederholm T, Vessby B, et al. Influence of a healthy Nordic diet on serum fatty acid composition and associations with blood lipoproteins - results from the NORDIET study. Food Nutr Res. 2014. 58:24114. doi:10.3402/fnr.v58.24114 | Intervention/Exposure
21 | Advice about diet and lifestyle does not reduce blood pressure in people with hypertension. Evidence-based Healthcare and Public Health. 2004;8(6):348-349. doi: 10.1016/j.ehbc.2004.09.005 | Intervention/Exposure; Publication status
22 | Aghaei N, Rouhani MH, Tabatabaei F, Larijani B, Azadbakht L. Effect of diverse low energy-dense versus healthy diet on metabolic outcomes in overweight/obese adolescents: a randomized controlled trial. Progress in Nutrition. Apr 2019;21:122-129. doi:10.23751/pn.v21i1-S.5721 | Intervention/Exposure
23 | Aghayan M, Hosseinpour-Niazi S, Bakhshi B, Mirmiran P, Azizi F. Trends in dietary food groups and Dietary Approach to Stop Hypertension (DASH) score among adults: A longitudinal study from the Tehran Lipid and Glucose Study, 2006-2017. Nutrition. Sep 2021;89doi:ARTN 111284 10.1016/j.nut.2021.111284 | Intervention/Exposure; Outcome
24 | Agheli N, Cloarec M, Jacotot B. Effect of dietary treatment on the lipid, lipoprotein and fatty acid compositions in type IV familial hypertriglyceridemia. Ann Nutr Metab. 1991;35(5):261-73. doi:10.1159/000177656 | Sample size/Power
25 | Agren JJ, Hanninen O, Julkunen A, et al. Fish diet, fish oil and docosahexaenoic acid rich oil lower fasting and postprandial plasma lipid levels. Eur J Clin Nutr. Nov 1996;50(11):765-71. | Intervention/Exposure; Comparator
26 | Aguas-Ayesa M, Yarnoz-Esquiroz P, Olazaran L, et al. Evaluation of Dietary and Alcohol Drinking Patterns in Patients with Excess Body Weight in a Spanish Cohort: Impact on Cardiometabolic Risk Factors. Nutrients. Nov 17 2023;15(22)doi:10.3390/nu15224824 | Study design; Outcome
27 | Ahiawodzi PD, Furtado JD, Mukamal KJ. Dietary Macronutrients and Circulating Nonesterified Fatty Acids: A Secondary Analysis of the OMNI Heart Crossover Trial. J Nutr. Jan 14 2023;152(12):2802-2807. doi:10.1093/jn/nxac187 | Intervention/Exposure
28 | Ahmad AF, Rich L, Koch H, et al. Effect of adding milk to black tea on vascular function in healthy men and women: a randomised controlled crossover trial. Food Funct. 2018. 9:6307-6314. doi:10.1039/c8fo01019f | Comparator
29 | Ahmadi E, Abdollahzad H, Pasdar Y, et al. Relationship Between the Consumption of Milk-Based Oils Including Butter and Kermanshah Ghee with Metabolic Syndrome: Ravansar Non-Communicable Disease Cohort Study. Diabetes Metab Syndr Obes. 2020. 13:1519-1530. doi:10.2147/dmso.S247412 | Study design
30 | Aigner A, Becher H, Jacobs S, et al. Low diet quality and the risk of stroke mortality: the multiethnic cohort study. Eur J Clin Nutr. 2018. 72:1035-1045. doi:10.1038/s41430-018-0103-4 | Intervention/Exposure
31 | Akbaraly T, Sabia S, Hagger-Johnson G, et al. Does overall diet in midlife predict future aging phenotypes? A cohort study. Am J Med. 2013. 126:411-419.e3. doi:10.1016/j.amjmed.2012.10.028 | Intervention/Exposure
32 | Akbaraly TN, Ferrie JE, Berr C, et al. Alternative Healthy Eating Index and mortality over 18 y of follow-up: results from the Whitehall II cohort. Am J Clin Nutr. 2011. 94:247-53. doi:10.3945/ajcn.111.013128 | Comparator
33 | AkbarySedigh A, Asghari G, Mahdavi M, Mirmiran P, Valizadeh M, Azizi F. The association of long-term calcium and dairy products intake in adolescence with carotid intima media thickness and metabolic syndrome in early adulthood: Tehran Lipid and Glucose Study. Nutr Metab (Lond). Apr 3 2023;20(1):21. doi:10.1186/s12986-023-00725-4 | Intervention/Exposure
34 | Akita S, Sacks FM, Svetkey LP, Conlin PR, Kimura G, Group DA-STCR. Effects of the Dietary Approaches to Stop Hypertension (DASH) diet on the pressure-natriuresis relationship. Hypertension. Jul 2003;42(1):8-13. doi:10.1161/01.HYP.0000074668.08704.6E | Intervention/Exposure
35 | Akrami A, Nikaein F, Babajafari S, et al. Comparison of the effects of flaxseed oil and sunflower seed oil consumption on serum glucose, lipid profile, blood pressure, and lipid peroxidation in patients with metabolic syndrome. Journal of Clinical Lipidology. 2018. 12:70-77. doi:10.1016/j.jacl.2017.11.004 | Intervention/Exposure
36 | Akter S, Mizoue T, Nanri A, et al. Low carbohydrate diet and all cause and cause-specific mortality. Clinical Nutrition. 2021. 40:2016-2024. doi:10.1016/j.clnu.2020.09.022 | Intervention/Exposure
37 | Al Suwaidi J. Dietary patterns and their association with acute coronary heart disease: Lessons from the REGARDS Study. Glob Cardiol Sci Pract. 2015;2015(4):56. doi:10.5339/gcsp.2015.56 | Intervention/Exposure
38 | Al Wattar B H, Dodds J, Placzek A, Beresford, et al. Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): A pragmatic multicentre randomised trial. PLoS Med. 2019. 16:e1002857. doi:10.1371/journal.pmed.1002857 | Intervention/Exposure; Outcome
39 | Alanbagy S. The Effects of Omega 3 Supplementation on Markers of Obesity and Endothelial Function [Thesis]. Arizona State University. 2014. | Study design; Publication status
40 | Alavinejad P, Farsi F, Rezazadeh A, et al. The effects of dark chocolate consumption on lipid profile, fasting blood sugar, liver enzymes, inflammation, and antioxidant status in patients with non-alcoholic fatty liver disease: a randomized, placebo-controlled, pilot study. Journal of Gastroenterology and Hepatology Research. 2015;4(11):1858-1864. doi: 10.17554/j.issn.2224-3992.2015.04.589 | Health status
41 | Albert BB, Derraik JGB, Xia YY, et al. Supplementation with milk enriched with complex lipids during pregnancy: A double-blind randomized controlled trial. PLoS One. 2021;16(2):e0244916. doi:10.1371/journal.pone.0244916 | Intervention/Exposure; Outcome
42 | Albertson AM, Affenito SG, Bauserman R, Holschuh NM, Eldridge AL, Barton BA. The Relationship of Ready-to-Eat Cereal Consumption to Nutrient Intake, Blood Lipids, and Body Mass Index of Children as They Age through Adolescence. Journal of the American Dietetic Association. Sep 2009;109(9):1557-1565. doi:10.1016/j.jada.2009.06.363 | Intervention/Exposure
43 | Al-Delaimy WK, Rimm E, Willett WC, Stampfer MJ, Hu FB. A prospective study of calcium intake from diet and supplements and risk of ischemic heart disease among men. Am J Clin Nutr. 2003;77(4):814-818. doi:10.1093/ajcn/77.4.814 | Intervention/Exposure; Comparator
44 | Aldrich ND, Reicks MM, Sibley SD, Redmon JB, Thomas W, Raatz SK. Varying protein source and quantity do not significantly improve weight loss, fat loss, or satiety in reduced energy diets among midlife adults. Nutrition Research. Feb 2011;31(2):104-112. doi:10.1016/j.nutres.2011.01.004 | Intervention/Exposure
45 | Al-Faris NA. Short-term consumption of a dark chocolate containing flavanols is followed by a significant decrease in normotensive population. Pakistan Journal of Nutrition. 2008;7(6):773-781. doi: 10.3923/pjn.2008.773.781 | Duration
46 | Alford BB, Blankenship AC, Hagen RD. The Effects of Variations in Carbohydrate, Protein, and Fat-Content of the Diet Upon Weight-Loss, Blood Values, and Nutrient Intake of Adult Obese Women. Journal of the American Dietetic Association. Apr 1990;90(4):534-540. | Intervention/Exposure
47 | Alharbi MH, Alharbi NHJ, Brnawi IA, Atiq EH. Implication of red meat consumption habits in serum uric acid levels and mood disorders among first-trimester pregnant women. BMC Nutr. Sep 29 2023;9(1):111. doi:10.1186/s40795-023-00769-y | Study design; Outcome
48 | Alhassan S, Reese KA, Mahurin J, et al. Blood lipid responses to plant stanol ester supplementation and aerobic exercise training. Metabolism. 2006. 55:541-9. doi:10.1016/j.metabol.2005.11.006 | Comparator; Sample size/Power
49 | Alias IZ Jr, Mdisa Z, Abdulkadir K, Ali O. The effect of increased consumption of edible palm oil on the nutritional status, lipid profiles and lipid peroxidation among malaysian aboriginestc. Malays J Nutr. 2002;8(2):137-156. | Country
50 | Alissa EM, Bahjri SM, Al-Ama N, et al. High cardiovascular risk in young Saudi males: cardiovascular risk factors, diet and inflammatory markers. Clin Chim Acta. 2006. 365:288-96. doi:10.1016/j.cca.2005.09.007 | Study design; Intervention/Exposure
51 | Allen JK, Becker DM, Kwiterovich PO, Lindenstruth KA, Curtis C. Effect of soy protein-containing isoflavones on lipoproteins in postmenopausal women. Menopause. Jan-Feb 2007;14(1):106-14. doi:10.1097/01.gme.0000229572.21635.49 | Intervention/Exposure; Comparator
52 | Allen RR, Carson L, Kwik-Uribe C, Evans EM, Erdman JW, Jr. Daily consumption of a dark chocolate containing flavanols and added sterol esters affects cardiovascular risk factors in a normotensive population with elevated cholesterol. J Nutr. Apr 2008;138(4):725-31. doi:10.1093/jn/138.4.725 | Intervention/Exposure
53 | Allison MA, Aragaki A, Eaton C, et al. Effect of dietary modification on incident carotid artery disease in postmenopausal women: results from the women’s health initiative dietary modification trial. Stroke. 2014. 45:1748-56. doi:10.1161/strokeaha.114.005096 | Intervention/Exposure
54 | Allman-Farinelli MA, Gomes K, Favaloro EJ, et al. A diet rich in high-oleic-acid sunflower oil favorably alters low-density lipoprotein cholesterol, triglycerides, and factor VII coagulant activity. J Am Diet Assoc. 2005. 105:1071-9. doi:10.1016/j.jada.2005.04.008 | Sample size/Power
55 | Almendingen K, Jordal O, Kierulf P, Sandstad B, Pedersen JI. Effects of partially hydrogenated fish oil, partially hydrogenated soybean oil, and butter on serum lipoproteins and Lp[a] in men. J Lipid Res. Jun 1995;36(6):1370-84 | Duration
56 | Almendingen K, Seljeflot I, Sandstad B, Pedersen JI. Effects of partially hydrogenated fish oil, partially hydrogenated soybean oil, and butter on hemostatic variables in men. Arterioscler Thromb Vasc Biol. Mar 1996;16(3):375-80. doi:10.1161/01.atv.16.3.375 | Duration; Outcome; Sample size/Power
57 | Alonso A, Beunza JJ, Delgado-Rodríguez M, et al. Low-fat dairy consumption and reduced risk of hypertension: the Seguimiento Universidad de Navarra (SUN) cohort. Am J Clin Nutr. 2005. 82:972-9. doi:10.1093/ajcn/82.5.972 | Comparator
58 | Alonso A, Steffen LM, Folsom AR. Dairy intake and changes in blood pressure over 9 years: the ARIC study. Eur J Clin Nutr. 2009. 63:1272-5. doi:10.1038/ejcn.2009.50 | Comparator
59 | Alper CM, Mattes RD. Peanut consumption improves indices of cardiovascular disease risk in healthy adults. J Am Coll Nutr. 2003;22(2):133-141. doi:10.1080/07315724.2003.10719286 | Sample size/Power
60 | Alphonse PA, Ramprasath V, Jones PJ. Effect of dietary cholesterol and plant sterol consumption on plasma lipid responsiveness and cholesterol trafficking in healthy individuals. Br J Nutr. Jan 2017;117(1):56-66. doi:10.1017/S0007114516004530 | Intervention/Exposure; Comparator
61 | Alphonse PA, Ramprasath V, Jones PJ. Effect of dietary cholesterol and plant sterol consumption on plasma lipid responsiveness and cholesterol trafficking in healthy individuals. Br J Nutr. Jan 2017;117(1):56-66. doi:10.1017/S0007114516004530 | Comparator
62 | AlSaleh A, O’Dell SD, Frost GS, et al. Interaction of PPARG Pro12Ala with dietary fat influences plasma lipids in subjects at cardiometabolic risk. J Lipid Res. 2011. 52:2298-2303. doi:10.1194/jlr.P019281 | Intervention/Exposure
63 | Altorf-van der Kuil W, Engberink MF, van Rooij FJ, et al. Dietary protein and risk of hypertension in a Dutch older population: the Rotterdam study. J Hypertens. Dec 2010;28(12):2394-400. doi:10.1097/HJH.0b013e32833eff63 | Intervention/Exposure
64 | Altorf-van der Kuil W, Engberink MF, Geleijnse JM, et al. Sources of dietary protein and risk of hypertension in a general Dutch population. Br J Nutr. 2012. 108:1897-903. doi:10.1017/s0007114512000049 | Intervention/Exposure
65 | Alvarez-Alvarez I, Zazpe I, Pérez de Rojas J, et al. Mediterranean diet, physical activity and their combined effect on all-cause mortality: The Seguimiento Universidad de Navarra (SUN) cohort. Preventive Medicine. 2018. 106:45-52. doi:10.1016/j.ypmed.2017.09.021 | Outcome
66 | Alvarez-Sala A, Blanco-Morales V, Cilla A, et al. A positive impact on the serum lipid profile and cytokines after the consumption of a plant sterol-enriched beverage with a milk fat globule membrane: a clinical study. Food Funct. 2018. 9:5209-5219. doi:10.1039/c8fo00353j | Intervention/Exposure; Comparator
67 | Alzubaidi LKA, Rajab HA, Aweed KF, Al-dulaimi FKY. Effect of Arabian yogurt and white cheese on some physiological parameters of human. Annals of Tropical Medicine and Public Health. 2020;23(13). doi:10.36295/asro.2020.231363 | Duration
68 | Amba V, Murphy G, Etemadi A, Wang S, Abnet CC, Hashemian M. Nut and Peanut Butter Consumption and Mortality in the National Institutes of Health-AARP Diet and Health Study. Nutrients. Jul 2 2019;11(7)doi:10.3390/nu11071508 | Intervention/Exposure
69 | Ambring A, Friberg P, Axelsen M, et al. Effects of a Mediterranean-inspired diet on blood lipids, vascular function and oxidative stress in healthy subjects. Clin Sci (Lond). 2004. 106:519-25. doi:10.1042/cs20030315 | Intervention/Exposure; Sample size/Power
70 | Amiano P, Chamosa S, Etxezarreta N, et al. Unprocessed red meat and processed meat consumption and risk of stroke in the Spanish cohort of the European Prospective Investigation into Cancer and Nutrition (EPIC). Eur J Clin Nutr. 2016. 70:313-9. doi:10.1038/ejcn.2015.150 | Comparator
71 | Andersen LB, Klausen K, Nisbeth O. Etårs effekt af sundhedsvejledning på livsstil og risikofaktorer for hjertesygdom [One-year effect of health counseling on life style and risk factors of heart disease]. Ugeskr Laeger. 2002;164(13):1814-1818. | Intervention/Exposure; Publication language
72 | Andersen CJ, Lee JY, Blesso CN, et al. Egg intake during carbohydrate restriction alters peripheral blood mononuclear cell inflammation and cholesterol homeostasis in metabolic syndrome. Nutrients. 2014. 6:2650-67. doi:10.3390/nu6072650 | Intervention/Exposure; Outcome
73 | Anderson JW, Garrity TF, Wood CL, Whitis SE, Smith BM, Oeltgen PR. Prospective, randomized, controlled comparison of the effects of low-fat and low-fat plus high-fiber diets on serum lipid concentrations. Am J Clin Nutr. Nov 1992;56(5):887-94. doi:10.1093/ajcn/56.5.887 | Intervention/Exposure
74 | Anderson JW, Gilliland SE. Effect of fermented milk (yogurt) containing Lactobacillus acidophilus L1 on serum cholesterol in hypercholesterolemic humans. J Am Coll Nutr. Feb 1999;18(1):43-50. doi:10.1080/07315724.1999.10718826 | Intervention/Exposure; Comparator
75 | Anderson JW, Hoie LH. Weight loss and lipid changes with low-energy diets: comparator study of milk-based versus soy-based liquid meal replacement interventions. J Am Coll Nutr. Jun 2005;24(3):210-6. doi:10.1080/07315724.2005.10719467 | Intervention/Exposure; Sample size/Power
76 | Anderson-Vasquez HE, Pérez-Martínez P, Ortega Fernández P, et al. Impact of the consumption of a rich diet in butter and it replacement for a rich diet in extra virgin olive oil on anthropometric, metabolic and lipid profile in postmenopausal women. Nutr Hosp. 2015. 31:2561-70. doi:10.3305/nh.2015.31.6.8732 | Sample size/Power
77 | Anderssen SA, Hjermann I, Urdal P, Torjesen PA, Holme I. Improved carbohydrate metabolism after physical training and dietary intervention in individuals with the “atherothrombogenic syndrome’. Oslo Diet and Exercise Study (ODES). A randomized trial. J Intern Med. Oct 1996;240(4):203-9. doi:10.1046/j.1365-2796.1996.22848000.x | Intervention/Exposure; Comparator
78 | Andrade I, Santos L, Ramos F. “Add-on" effect of phytosterols-enriched fermented milk on lipids and markers of cholesterol metabolism in statin-treated elderly patients. Steroids. Jul 2015;99(Pt B):293-8. doi:10.1016/j.steroids.2015.03.007 | Intervention/Exposure; Health status
79 | Andrade S, Borges N. Effect of fermented milk containing Lactobacillus acidophilus and Bifidobacterium longum on plasma lipids of women with normal or moderately elevated cholesterol. J Dairy Res. 2009. 76:469-74. doi:10.1017/s0022029909990173 | Comparator
80 | Andueza N, Martin-Calvo N, Navas-Carretero S, et al. The ALINFA Intervention Improves Diet Quality and Nutritional Status in Children 6 to 12 Years Old. Nutrients. May 18 2023;15(10)doi:10.3390/nu15102375 | Intervention/Exposure
81 | Anil S, Charlton KE, Tapsell LC, et al. Identification of dietary patterns associated with blood pressure in a sample of overweight Australian adults. J Hum Hypertens. Nov 2016;30(11):672-678. doi:10.1038/jhh.2016.10 | Study design; Intervention/Exposure
82 | Antonopoulou S, Detopoulou M, Fragopoulou E, et al. Consumption of yogurt enriched with polar lipids from olive oil by-products reduces platelet sensitivity against platelet activating factor and inflammatory indices: a randomized, double-blind clinical trial. Human Nutrition & Metabolism. Jun 2022;28doi:ARTN 200145 10.1016/j.hnm.2022.200145 | Comparator
83 | Aoyagi Y, Park S, Matsubara S, et al. Habitual intake of fermented milk products containing Lactobacillus casei strain Shirota and a reduced risk of hypertension in older people. Benef Microbes. Feb 7 2017;8(1):23-29. doi:10.3920/BM2016.0135 | Intervention/Exposure; Comparator
84 | Appel LJ, Champagne CM, Harsha DW, et al. Effects of comprehensive lifestyle modification on blood pressure control: main results of the PREMIER clinical trial. JAMA. 2003;289(16):2083-2093. doi:10.1001/jama.289.16.2083 | Intervention/Exposure
85 | Appel, LJ, Miller, ER, 3rd, Jee, et al. Effect of dietary patterns on serum homocysteine: results of a randomized, controlled feeding study. Circulation. Aug 22 2000;102(8):852-7. doi:10.1161/01.cir.102.8.852 | Intervention/Exposure
86 | Appel LJ, Moore TJ, Obarzanek E, et al. A clinical trial of the effects of dietary patterns on blood pressure. DASH Collaborative Research Group. N Engl J Med. Apr 17 1997;336(16):1117-24. doi:10.1056/NEJM199704173361601 | Intervention/Exposure
87 | Appel LJ, Sacks FM, Carey VJ, et al. Effects of protein, monounsaturated fat, and carbohydrate intake on blood pressure and serum lipids: results of the OmniHeart randomized trial. JAMA. 2005. 294:2455-64. doi:10.1001/jama.294.19.2455 | Intervention/Exposure
88 | Appleby PN, Crowe FL, Bradbury KE, et al. Mortality in vegetarians and comparable nonvegetarians in the United Kingdom. Am J Clin Nutr. 2016. 103:218-30. doi:10.3945/ajcn.115.119461 | Comparator
89 | Appleby PN, Thorogood M, McPherson K, et al. Associations between plasma lipid concentrations and dietary, lifestyle and physical factors in the Oxford Vegetarian Study. Journal of Human Nutrition and Dietetics. Oct 1995;8(5):305-314. doi:DOI 10.1111/j.1365-277X.1995.tb00324.x | Comparator
90 | Archer WR, Lamarche B, St-Pierre AC, et al. High carbohydrate and high monounsaturated fatty acid diets similarly affect LDL electrophoretic characteristics in men who are losing weight. J Nutr. Oct 2003;133(10):3124-9. doi:10.1093/jn/133.10.3124 | Intervention/Exposure
91 | Arefhosseini SR, Edwards CA, Malkova D, et al. Effect of advice to increase carbohydrate and reduce fat intake on dietary profile and plasma lipid concentrations in healthy postmenopausal women. Ann Nutr Metab. 2009;54(2):138-44. doi:10.1159/000210435 | Intervention/Exposure
92 | Argyridou S, Zaccardi F, Davies MJ, et al. Relevance of physical function in the association of red and processed meat intake with all-cause, cardiovascular, and cancer mortality. Nutr Metab Cardiovasc Dis. 2019. 29:1308-1315. doi:10.1016/j.numecd.2019.06.019 | Comparator
93 | Arikan I, Metintas S, Kalyoncu C, et al. Evaluation of metabolic syndrome prevalence in semi-rural areas of Central Anatolia, Turkey. Saudi Med J. Aug 2009;30(8):1073-80 | Study design
94 | Arnarson A, Olafsdottir A, Ramel A, et al. Sensory analysis and consumer surveys of fat- and salt-reduced meat products and their use in an energy-reduced diet in overweight individuals. International Journal of Food Sciences and Nutrition. Dec 2011;62(8):872-880. doi:10.3109/09637486.2011.589376 | Duration; Sample size/Power
95 | Arnlöv J, Lind L, Sundström J, et al. Insulin resistance, dietary fat intake and blood pressure predict left ventricular diastolic function 20 years later. Nutr Metab Cardiovasc Dis. 2005. 15:242-9. doi:10.1016/j.numecd.2004.10.002 | Intervention/Exposure
96 | Aro A, Jauhiainen M, Partanen R, et al. Stearic acid, trans fatty acids, and dairy fat: effects on serum and lipoprotein lipids, apolipoproteins, lipoprotein(a), and lipid transfer proteins in healthy subjects. Am J Clin Nutr. 1997. 65:1419-26. doi:10.1093/ajcn/65.5.1419 | Intervention/Exposure; Comparator
97 | Artaud-Wild SM, Connor SL, Sexton G, Connor WE. Differences in coronary mortality can be explained by differences in cholesterol and saturated fat intakes in 40 countries but not in France and Finland. A paradox. Circulation. 1993;88(6):2771-2779. doi:10.1161/01.cir.88.6.2771 | Intervention/Exposure
98 | Artinian NT, Schim SM, Vander Wal JS, et al. Eating patterns and cardiovascular disease risk in a Detroit Mexican American population. Public Health Nurs. Sep-Oct 2004;21(5):425-34. doi:10.1111/j.0737-1209.2004.21506.x | Study design; Intervention/Exposure
99 | Asadi Z, Shafiee M, Sadabadi F, et al. Association of dietary patterns and risk of cardiovascular disease events in the MASHAD cohort study. J Hum Nutr Diet. 2019. 32:789-801. doi:10.1111/jhn.12669 | Intervention/Exposure
100 | Asato L, Wang MF, Chan YC, et al. Effect of egg white on serum cholesterol concentration in young women. J Nutr Sci Vitaminol (Tokyo). Apr 1996;42(2):87-96. doi:10.3177/jnsv.42.87 | Intervention/Exposure
101 | Ascherio A, Rimm EB, Giovannucci EL, et al. A prospective study of nutritional factors and hypertension among US men. Circulation. 1992;86(5):1475-1484. doi:10.1161/01.cir.86.5.1475 | Intervention/Exposure
102 | Ascherio A, Willett WC, Rimm EB, Giovannucci EL, Stampfer MJ. Dietary iron intake and risk of coronary disease among men. Circulation. 1994;89(3):969-974. doi:10.1161/01.cir.89.3.969 | Intervention/Exposure
103 | Ascherio A, Hennekens C, Willett WC, et al. Prospective study of nutritional factors, blood pressure, and hypertension among US women. Hypertension. May 1996;27(5):1065-1072. doi:Doi 10.1161/01.Hyp.27.5.1065 | Intervention/Exposure
104 | Ascherio A, Rimm EB, Giovannucci EL, et al. Dietary fat and risk of coronary heart disease in men: cohort follow up study in the United States. BMJ. Jul 13 1996;313(7049):84-90. doi:10.1136/bmj.313.7049.84 | Intervention/Exposure
105 | Ascherio A. Trans fatty acids and blood lipids. Atherosclerosis Supplements. 2006. 7:25-27. doi:10.1016/j.atherosclerosissup.2006.04.018 | Study design; Intervention/Exposure
106 | Asghari G, Yuzbashian E, Mirmiran P, et al. Dietary Approaches to Stop Hypertension (DASH) Dietary Pattern Is Associated with Reduced Incidence of Metabolic Syndrome in Children and Adolescents. J Pediatr. 2016. 174:178-184.e1. doi:10.1016/j.jpeds.2016.03.077 | Intervention/Exposure
107 | Asghari G, Yuzbashian E, Mirmiran P, et al. Fast Food Intake Increases the Incidence of Metabolic Syndrome in Children and Adolescents: Tehran Lipid and Glucose Study. PLoS One. 2015;10(10):e0139641. doi:10.1371/journal.pone.0139641 | Intervention/Exposure
108 | Ashaye A, Gaziano J, Djoussé L. Red meat consumption and risk of heart failure in male physicians. Nutr Metab Cardiovasc Dis. 2011. 21:941-6. doi:10.1016/j.numecd.2010.03.009 | Intervention/Exposure; Comparator
109 | Ashen MD, Blumenthal RS. Low HDL Cholesterol Levels. New England Journal of Medicine. 2005;353(12):1252-1260. doi:10.1056/nejmcp044370 | Study design
110 | Ashton EL, Pomeroy S, Foster JE, Kaye RS, Nestel PJ, Ball M. Diet high in monounsaturated fat does not have a different effect on arterial elasticity than a low-fat, high-carbohydrate diet. J Am Diet Assoc. 2000;100(5):537-542. doi:10.1016/S0002-8223(00)00167-X | Intervention/Exposure; Sample size/Power
111 | Ashton E, Ball M. Effects of soy as tofu vs meat on lipoprotein concentrations. Eur J Clin Nutr. 2000. 54:14-9. doi:10.1038/sj.ejcn.1600885 | Intervention/Exposure; Comparator
112 | Ashton EL, Dalais FS, Ball MJ. Effect of meat replacement by tofu on CHD risk factors including copper induced LDL oxidation. J Am Coll Nutr. Nov-Dec 2000;19(6):761-7. doi:10.1080/07315724.2000.10718067 | Intervention/Exposure; Comparator
113 | Assaf-Balut C, de la Torre NG, Durán A, et al. An Early, Universal Mediterranean Diet-Based Intervention in Pregnancy Reduces Cardiovascular Risk Factors in the “Fourth Trimester”. Journal of Clinical Medicine. Sep 2019;8(9)doi:ARTN 149910.3390/jcm8091499 | Intervention/Exposure
114 | Assunção ML, Ferreira HS, dos Santos AF, et al. Effects of dietary coconut oil on the biochemical and anthropometric profiles of women presenting abdominal obesity. Lipids. 2009. 44:593-601. doi:10.1007/s11745-009-3306-6 | Sample size/Power
115 | Astrup A. Yogurt and dairy product consumption to prevent cardiometabolic diseases: epidemiologic and experimental studies. Am J Clin Nutr. May 2014;99(5 Suppl):1235S-42S. doi:10.3945/ajcn.113.073015 | Study design
116 | Astrup AV. Saturated fat and CVD: the role of milk products in reducing risk. Can Nurse. Jan 2012;108(1):45. | Study design; Publication status
117 | Asztalos B, Lefevre M, Wong L, et al. Differential response to low-fat diet between low and normal HDL-cholesterol subjects. J Lipid Res. Mar 2000;41(3):321-8. | Intervention/Exposure
118 | Ataie-Jafari A, Hosseini S, Alavi-Majd H, Tahbaz F. Effects of milk replacement with regular yogurt and probiotic yogurt on blood lipid profiles of hypercholesterolemic and normocholesterolemic individuals. Iranian Journal of Diabetes and Lipid Disorders. 2007;7(2):239-244. | Publication language; Comparator
119 | Ataie-Jafari A, Larijani B, Alavi Majd H, et al. Cholesterol-lowering effect of probiotic yogurt in comparison with ordinary yogurt in mildly to moderately hypercholesterolemic subjects. Ann Nutr Metab. 2009. 54:22-7. doi:10.1159/000203284 | Comparator; Sample size/Power
120 | Atalić B, Toth J, Atalić V, et al. Red and processed meat and cardiovascular risk factors. Acta Med Croatica. Jun 2013;67(3):211-8 | Study design
121 | Atkins JL, Whincup PH, Morris RW, et al. Dietary patterns and the risk of CVD and all-cause mortality in older British men. Br J Nutr. 2016. 116:1246-1255. doi:10.1017/s0007114516003147 | Intervention/Exposure
122 | Atkinson C, Whitley E, Ness A, et al. Associations between types of dietary fat and fish intake and risk of stroke in the Caerphilly Prospective Study (CaPS). Public Health. Jun 2011;125(6):345-348. doi:10.1016/j.puhe.2011.03.002 | Intervention/Exposure
123 | Aude YW, Agatston AS, Lopez-Jimenez F, et al. The national cholesterol education program diet vs a diet lower in carbohydrates and higher in protein and monounsaturated fat: A randomized trial. Archives of Internal Medicine. 2004. 164:2141-2146. doi:10.1001/archinte.164.19.2141 | Intervention/Exposure
124 | Austel A, Ranke C, Wagner N, et al. Weight loss with a modified Mediterranean-type diet using fat modification: a randomized controlled trial. Eur J Clin Nutr. 2015. 69:878-84. doi:10.1038/ejcn.2015.11 | Intervention/Exposure
125 | Avalos EE, Barrett-Connor E, Kritz-Silverstein D, et al. Is dairy product consumption associated with the incidence of CHD?. Public Health Nutr. 2013. 16:2055-63. doi:10.1017/s1368980012004168 | Comparator
126 | Avelino AP, Oliveira GM, Ferreira CC, et al. Additive effect of linseed oil supplementation on the lipid profiles of older adults. Clin Interv Aging. 2015. 10:1679-85. doi:10.2147/cia.S75538 | Intervention/Exposure
127 | Azadbakht L, Nurbakhsh S. Effect of soy drink replacement in a weight reducing diet on anthropometric values and blood pressure among overweight and obese female youths. Asia Pac J Clin Nutr. 2011;20(3):383-389. | Intervention/Exposure
128 | Azadbakht L, Haghighatdoost F, Karimi G, et al. Effect of consuming salad and yogurt as preload on body weight management and cardiovascular risk factors: a randomized clinical trial. International Journal of Food Sciences and Nutrition. Jun 2013;64(4):392-399. doi:10.3109/09637486.2012.753039 | Intervention/Exposure; Outcome
129 | Azadbakht L, Izadi V, Ehsani S, et al. Effects of the Dietary Approaches to Stop Hypertension (DASH) Eating Plan on the Metabolic Side Effects of Corticosteroid Medications. J Am Coll Nutr. May-Jun 2016;35(4):285-90. doi:10.1080/07315724.2014.991459 | Intervention/Exposure
130 | Azadbakht L, Izadi V, Surkan PJ, et al. Effect of a High Protein Weight Loss Diet on Weight, High-Sensitivity C-Reactive Protein, and Cardiovascular Risk among Overweight and Obese Women: A Parallel Clinical Trial. Int J Endocrinol. 2013. 2013:971724. doi:10.1155/2013/971724 | Intervention/Exposure
131 | Azadbakht L, Kimiagar M, Mehrabi Y, et al. Dietary soya intake alters plasma antioxidant status and lipid peroxidation in postmenopausal women with the metabolic syndrome. Br J Nutr. 2007. 98:807-13. doi:10.1017/s0007114507746871 | Intervention/Exposure; Outcome
132 | Azadbakht L, Kimiagar M, Mehrabi Y, et al. Soy consumption, markers of inflammation, and endothelial function: a cross-over study in postmenopausal women with the metabolic syndrome. Diabetes Care. Apr 2007;30(4):967-73. doi:10.2337/dc06-2126 | Outcome
133 | Azadbakht L, Kimiagar M, Mehrabi Y, et al. Soy inclusion in the diet improves features of the metabolic syndrome: a randomized crossover study in postmenopausal women. Am J Clin Nutr. Mar 2007;85(3):735-41. doi:10.1093/ajcn/85.3.735 | Study design; Publication status
134 | Azadbakht L, Kimiagar M, Mehrabi Y, et al. Soy inclusion in the diet improves features of the metabolic syndrome: a randomized crossover study in postmenopausal women. Am J Clin Nutr. Mar 2007;85(3):735-41. doi:10.1093/ajcn/85.3.735 | Country
135 | Azadbakht L, Mirmiran P, Azizi F. Predictors of cardiovascular risk factors in Tehranian adults: diet and lifestyle. East Mediterr Health J. Jan-Mar 2006;12(1-2):88-97 | Intervention/Exposure; Country
136 | Azadbakht L, Mirmiran P, Esmaillzadeh A, et al. Beneficial effects of a Dietary Approaches to Stop Hypertension eating plan on features of the metabolic syndrome. Diabetes Care. 2005. 28:2823-31. doi:10.2337/diacare.28.12.2823 | Intervention/Exposure
137 | Azadbakht L, Mirmiran P, Esmaillzadeh A, et al. Better dietary adherence and weight maintenance achieved by a long-term moderate-fat diet. Br J Nutr. Feb 2007;97(2):399-404. doi:10.1017/S0007114507328602 | Intervention/Exposure; Country
138 | Azzannabillah KM, Wirjatmadi. Saturated fat acid food consumption correlation with hypertension in elderly woman. Indian Journal of Public Health Research & Development. 2020;11(3):1588-1592. | Study design; Intervention/Exposure
139 | Baba NH, Sawaya S, Torbay N, Habbal Z, Azar S, Hashim SA. High protein vs high carbohydrate hypoenergetic diet for the treatment of obese hyperinsulinemic subjects. Int J Obes Relat Metab Disord. Nov 1999;23(11):1202-6. doi:10.1038/sj.ijo.0801064 | Intervention/Exposure; Sample size/Power
140 | Babio N, Becerra-Tomás N, Martínez-González MA, et al. Consumption of Yogurt, Low-Fat Milk, and Other Low-Fat Dairy Products Is Associated with Lower Risk of Metabolic Syndrome Incidence in an Elderly Mediterranean Population. J Nutr. 2015;145(10):2308-2316. doi:10.3945/jn.115.214593 | Comparator
141 | Babio N, Sorli M, Bullo M, et al. Association between red meat consumption and metabolic syndrome in a Mediterranean population at high cardiovascular risk: cross-sectional and 1-year follow-up assessment. Nutr Metab Cardiovasc Dis. 2012;22(3):200-7. doi:10.1016/j.numecd.2010.06.011 | Intervention/Exposure; Comparator
142 | Badali T, Arefhosseini S, Rooholahzadegan F, Tutunchi H, Ebrahimi-Mameghani M. The effect of DASH diet on atherogenic indices, pro-oxidant-antioxidant balance, and liver steatosis in obese adults with non-alcoholic fatty liver disease: A double-blind controlled randomized clinical trial. Health Promot Perspect. 2023;13(1):77-87. doi:10.34172/hpp.2023.10 | Intervention/Exposure; Health status
143 | Baden MY, Shan Z, Wang F, et al. Quality of Plant-Based Diet and Risk of Total, Ischemic, and Hemorrhagic Stroke. Neurology. Apr 13 2021;96(15):e1940-e1953. doi:10.1212/WNL.0000000000011713 | Intervention/Exposure
144 | Bae CY, Keenan JM, Fontaine P, Wenz J, Ripsin CM, McCaffrey DJ. Plasma lipid response and nutritional adequacy in hypercholesterolemic subjects on the American Heart Association Step-One Diet. Arch Fam Med. Jul 1993;2(7):765-72. doi:10.1001/archfami.2.7.765 | Intervention/Exposure
145 | Bae CY, Keenan JM, Wenz J, McCaffrey DJ. A clinical trial of the American Heart Association step one diet for treatment of hypercholesterolemia. J Fam Pract. Sep 1991;33(3):249-54. | Intervention/Exposure
146 | Bae YJ, Yu KW, Lee KH, Jang KI. Association of the Healthy Eating Index with Metabolic Abnormalities among Middle-Aged Adults Living in Single-Person Households in Korea. Nutrients. Nov 2021;13(11)doi:10.3390/nu13113937 | Study design; Outcome
147 | Baer DJ, Judd JT, Clevidence BA, Tracy RP. Dietary fatty acids affect plasma markers of inflammation in healthy men fed controlled diets: a randomized crossover study. Am J Clin Nutr. Jun 2004;79(6):969-73. doi:10.1093/ajcn/79.6.969 | Intervention/Exposure
148 | Baer JT. Improved Plasma-Cholesterol Levels in Men after a Nutrition Education-Program at the Worksite. Journal of the American Dietetic Association. Jun 1993;93(6):658-663. doi:Doi 10.1016/0002-8223(93)91672-D | Intervention/Exposure
149 | Baik I, Lee M, Jun NR, Lee JY, Shin C. A healthy dietary pattern consisting of a variety of food choices is inversely associated with the development of metabolic syndrome. Nutr Res Pract. Jun 2013;7(3):233-41. doi:10.4162/nrp.2013.7.3.233 | Intervention/Exposure; Comparator
150 | Baila-Rueda L, Mateo-Gallego R, Pérez-Calahorra S, et al. Effect of different fat-enriched meats on non-cholesterol sterols and oxysterols as markers of cholesterol metabolism: Results of a randomized and cross-over clinical trial. Nutrition Metabolism and Cardiovascular Diseases. Sep 2015;25(9):853-859. doi:10.1016/j.numecd.2015.06.008 | Duration
151 | Bajracharya R, Kaaks R, Katzke V. Food Sources of Animal Protein in Relation to Overall and Cause-Specific Mortality-Causal Associations or Confounding? An Analysis of the EPIC-Heidelberg Cohort. Nutrients. Aug 2023;15(15)doi:10.3390/nu15153322 | Comparator
152 | Gray M, Baldwin N, Bae S, Ramachandran R, et al. Dietary patterns and risk of non-alcoholic fatty liver disease (NAFLD): A 25-year follow up from the Coronary Artery Risk Development in Young Adults (CARDIA) Study. Gastroenterology. May 2021;160:S832 doi:10.1016/S0016-5085(21)02715-3 | Intervention/Exposure; Outcome
153 | Bañuls C, Martínez-Triguero ML, López-Ruiz A, et al. Evaluation of cardiovascular risk and oxidative stress parameters in hypercholesterolemic subjects on a standard healthy diet including low-fat milk enriched with plant sterols. J Nutr Biochem. 2010. 21:881-6. doi:10.1016/j.jnutbio.2009.07.001 | Comparator; Sample size/Power
154 | Bañuls C, Martínez-Triguero ML, López-Ruiz A, et al. Serum lipid responses to phytosterol-enriched milk in a moderate hypercholesterolemic population is not affected by apolipoprotein E polymorphism or diameter of low-density lipoprotein particles. Eur J Clin Nutr. 2011. 65:255-61. doi:10.1038/ejcn.2010.241 | Intervention/Exposure; Comparator
155 | Baran D, Sorensen A, Grimes J, et al. Dietary modification with dairy products for preventing vertebral bone loss in premenopausal women: a three-year prospective study. J Clin Endocrinol Metab. 1990. 70:264-70. doi:10.1210/jcem-70-1-264 | Sample size/Power
156 | Barati M, Jabbari M, Teymoori F, et al. Dairy-originated digestion-resistant and bioactive peptides increase the risk of hypertension: Tehran Lipid and Glucose Study. Hypertens Res. Sep 2021;44(9):1194-1204. doi:10.1038/s41440-021-00692-4 | Intervention/Exposure
157 | Bard JM, Drouet L, Lairon D, et al. Effect of milk fat on LDL cholesterol and other cardiovascular risk markers in healthy humans: the INNOVALAIT project. Eur J Clin Nutr. Feb 2020;74(2):285-296. doi:10.1038/s41430-019-0528-4 | Intervention/Exposure
158 | Barnard RJ. Effects of life-style modification on serum lipids. Arch Intern Med. Jul 1991;151(7):1389-94. | Intervention/Exposure; Duration
159 | Barr SI, McCarron DA, Heaney RP, et al. Effects of increased consumption of fluid milk on energy and nutrient intake, body weight, and cardiovascular risk factors in healthy older adults. J Am Diet Assoc. Jul 2000;100(7):810-7. doi:10.1016/S0002-8223(00)00236-4 | Comparator
160 | Barr SL, Ramakrishnan R, Johnson C, Holleran S, Dell RB, Ginsberg HN. Reducing total dietary fat without reducing saturated fatty acids does not significantly lower total plasma cholesterol concentrations in normal males. Am J Clin Nutr. 1992;55(3):675-681. doi:10.1093/ajcn/55.3.675 | Intervention/Exposure; Sample size/Power
161 | Barrubés L, Babio N, Mena-Sánchez G, et al. Dairy product consumption and risk of colorectal cancer in an older mediterranean population at high cardiovascular risk. Int J Cancer. 2018;143(6):1356-1366. doi:10.1002/ijc.31540 | Outcome
162 | Basciani S, Camajani E, Contini S, et al. Very-Low-Calorie Ketogenic Diets With Whey, Vegetable, or Animal Protein in Patients With Obesity: A Randomized Pilot Study. J Clin Endocrinol Metab. 2020;105(9):dgaa336. doi:10.1210/clinem/dgaa336 | Intervention/Exposure
163 | Bass JA, Moore TA, Stewart KJ. Coronary heart disease risk factors in children and adolescents. Preventive Cardiology. 1999;2(1):8-12. | Study design
164 | Baulderstone L, Yaxley A, Luszcz M, Miller M. Diet Liberalisation in Older Australians Decreases Frailty without Increasing the Risk of Developing Chronic Disease. Journal of Frailty & Aging. 2012;1(4):174-182. | Intervention/Exposure
165 | Baum JA, Teng H, Erdman JW, Jr., et al. Long-term intake of soy protein improves blood lipid profiles and increases mononuclear cell low-density-lipoprotein receptor messenger RNA in hypercholesterolemic, postmenopausal women. Am J Clin Nutr. Sep 1998;68(3):545-51. doi:10.1093/ajcn/68.3.545 | Intervention/Exposure; Comparator
166 | Baumgartner S, Kelly ER, van der Made S, et al. The influence of consuming an egg or an egg-yolk buttermilk drink for 12 wk on serum lipids, inflammation, and liver function markers in human volunteers. Nutrition. Oct 2013;29(10):1237-44. doi:10.1016/j.nut.2013.03.020 | Intervention/Exposure; Comparator
167 | Baumgartner S, Mensink RP, Husche C, Lutjohann D, Plat J. Effects of plant sterol- or stanol-enriched margarine on fasting plasma oxyphytosterol concentrations in healthy subjects. Atherosclerosis. Apr 2013;227(2):414-9. doi:10.1016/j.atherosclerosis.2013.01.012 | Comparator
168 | Bautista LE, Herran OF, Serrano C. Effects of palm oil and dietary cholesterol on plasma lipoproteins: results from a dietary crossover trial in free-living subjects. Eur J Clin Nutr. Sep 2001;55(9):748-54. doi:10.1038/sj.ejcn.1601218 | Sample size/Power
169 | Baxheinrich A, Stratmann B, Lee-Barkey YH, Tschoepe D, Wahrburg U. Effects of a rapeseed oil-enriched hypoenergetic diet with a high content of alpha-linolenic acid on body weight and cardiovascular risk profile in patients with the metabolic syndrome. Br J Nutr. Aug 2012;108(4):682-91. doi:10.1017/S0007114512002875 | Intervention/Exposure
170 | Bazzano LA, Hu T, Reynolds K, et al. Effects of low-carbohydrate and low-fat diets: a randomized trial. Ann Intern Med. Sep 2 2014;161(5):309-18. doi:10.7326/M14-0180 | Intervention/Exposure
171 | Beasley JM, Ange BA, Anderson CAM, et al. Associations Between Macronutrient Intake and Self-reported Appetite and Fasting Levels of Appetite Hormones: Results From the Optimal Macronutrient Intake Trial to Prevent Heart Disease. American Journal of Epidemiology. Apr 1 2009;169(7):893-900. doi:10.1093/aje/kwn415 | Intervention/Exposure
172 | Beauchesne-Rondeau E, Gascon A, Bergeron J, Jacques H. Plasma lipids and lipoproteins in hypercholesterolemic men fed a lipid-lowering diet containing lean beef, lean fish, or poultry. Am J Clin Nutr. Mar 2003;77(3):587-93. doi:10.1093/ajcn/77.3.587 | Sample size/Power
173 | Becerra-Tomás N, Babio N, Martínez-González MÁ, et al. Replacing red meat and processed red meat for white meat, fish, legumes or eggs is associated with lower risk of incidence of metabolic syndrome. Clin Nutr. 2016;35(6):1442-1449 | Outcome; Comparator
174 | Beckmann SL, Os I, Kjeldsen SE, Eide IK, Westheim AS, Hjermann I. Effect of dietary counselling on blood pressure and arterial plasma catecholamines in primary hypertension. Am J Hypertens. 1995;8(7):704-11. doi:10.1016/0895-7061(95)00122-6 | Intervention/Exposure
175 | Bédard A, Corneau L, Vohl MC, Dodin S, Lemieux S. Effect of the Mediterranean Diet on the Lipid-Lipoprotein Profile: Is It Influenced by the Family History of Dyslipidemia? J Nutrigenet Nutrigenomics. 2014;7(4-6):177-187 | Intervention/Exposure
176 | Bekkouche L, Bouchenak M, Malaisse WJ, Yahia DA. The Mediterranean diet adoption improves metabolic, oxidative, and inflammatory abnormalities in Algerian metabolic syndrome patients. Horm Metab Res. Apr 2014;46(4):274-82. doi:10.1055/s-0033-1363657 | Study design; Intervention/Exposure
177 | Belin RJ, Greenland P, Allison M, et al. Diet quality and the risk of cardiovascular disease: the Women’s Health Initiative (WHI). Am J Clin Nutr. Jul 2011;94(1):49-57. doi:10.3945/ajcn.110.011221 | Comparator
178 | Bellavia A, Stilling F, Wolk A. High red meat intake and all-cause cardiovascular and cancer mortality: is the risk modified by fruit and vegetable intake? Am J Clin Nutr. Oct 2016;104(4):1137-1143. doi:10.3945/ajcn.116.135335 | Comparator
179 | Bellido C, Lopez-Miranda J, Perez-Martinez P, et al. The Mediterranean and CHO diets decrease VCAM-1 and E-selectin expression induced by modified low-density lipoprotein in HUVECs. Nutr Metab Cardiovasc Dis. Dec 2006;16(8):524-30. doi:10.1016/j.numecd.2005.09.007 | Intervention/Exposure; Comparator; Sample size/Power
180 | Bellikci-Koyu E, Sarer-Yurekli BP, Akyon Y, et al. Effects of Regular Kefir Consumption on Gut Microbiota in Patients with Metabolic Syndrome: A Parallel-Group, Randomized, Controlled Study. Nutrients. Sep 4 2019;11(9)doi:10.3390/nu11092089 | Sample size/Power
181 | Bellikci-Koyu E, Sarer-Yurekli BP, Karagozlu C, Aydin-Kose F, Ozgen AG, Buyuktuncer Z. Probiotic kefir consumption improves serum apolipoprotein A1 levels in metabolic syndrome patients: a randomized controlled clinical trial. Nutr Res. Jun 2022;102:59-70. doi:10.1016/j.nutres.2022.02.006 | Intervention/Exposure
182 | Bel-Serrat S, Mouratidou T, Börnhorst C, et al. Food consumption and cardiovascular risk factors in European children: the IDEFICS study. Pediatr Obes. 2013;8(3):225-236. doi:10.1111/j.2047-6310.2012.00107.x | Study design; Outcome
183 | Beltrán-Barrientos LM, González-Córdova AF, Hernández-Mendoza A, et al. Randomized double-blind controlled clinical trial of the blood pressure-lowering effect of fermented milk with Lactococcus lactis: A pilot study. J Dairy Sci. Apr 2018;101(4):2819-2825. doi:10.3168/jds.2017-13189 | Intervention/Exposure; Comparator
184 | Bemelmans WJ, Broer J, de Vries JH, Hulshof KF, May JF, Meyboom-De Jong B. Impact of Mediterranean diet education versus posted leaflet on dietary habits and serum cholesterol in a high risk population for cardiovascular disease. Public Health Nutr. 2000;3(3):273-283. doi:10.1017/s1368980000000318 | Intervention/Exposure; Comparator
185 | Bemelmans WJ, Broer J, Feskens EJ, et al. Effect of an increased intake of alphalinolenic acid and group nutritional education on cardiovascular risk factors: the Mediterranean Alpha-linolenic Enriched Groningen Dietary Intervention (MARGARIN) study. Am J Clin Nutr. Feb 2002;75(2):221-7. doi:10.1093/ajcn/75.2.221 | Intervention/Exposure
186 | Bemelmans WJE, Broer J, Hulshof KFAM, Siero FW, May JF, Meyboom-de Jong B. Long-term effects of nutritional group education for persons at high cardiovascular risk. European Journal of Public Health. Sep 2004;14(3):240-245. doi:DOI 10.1093/eurpub/14.3.240 | Intervention/Exposure
187 | Benatar JR, Jones E, White H, Stewart RA. A randomized trial evaluating the effects of change in dairy food consumption on cardio-metabolic risk factors. Eur J Prev Cardiol. Nov 2014;21(11):1376-86. doi:10.1177/2047487313493567 | Intervention/Exposure; Comparator
188 | Benatar JR, Stewart RA. The effects of changing dairy intake on trans and saturated fatty acid levels- results from a randomized controlled study. Nutr J. Apr 3 2014;13:32. doi:10.1186/1475-2891-13-32 | Outcome
189 | Ben-Avraham S, Harman-Boehm I, Schwarzfuchs D, Shai I. Dietary strategies for patients with type 2 diabetes in the era of multi-approaches; review and results from the Dietary Intervention Randomized Controlled Trial (DIRECT). Diabetes Res Clin Pract. Dec 2009;86 Suppl 1:S41-8. doi:10.1016/S0168-8227(09)70008-7 | Intervention/Exposure; Health status; Outcome
190 | Bendinelli B, Masala G, Saieva C, et al. Fruit, vegetables, and olive oil and risk of coronary heart disease in Italian women: the EPICOR Study. Am J Clin Nutr. Feb 2011;93(2):275-83. doi:10.3945/ajcn.110.000521 | Intervention/Exposure
191 | Bendtsen LQ, Lorenzen JK, Larsen TM, et al. Associations between dairy protein intake and body weight and risk markers of diabetes and CVD during weight maintenance. Br J Nutr. 2014;111(5):944-953. doi:10.1017/S0007114513003322 | Intervention/Exposure
192 | Benito P, Caballero J, Moreno J, et al. Effects of milk enriched with omega-3 fatty acid, oleic acid and folic acid in patients with metabolic syndrome. Clin Nutr. 2006;25(4):581-587. doi:10.1016/j.clnu.2005.12.006 | Comparator
193 | Benito P, Nelson GJ, Kelley DS, Bartolini G, Schmidt PC, Simon V. The effect of conjugated linoleic acid on plasma lipoproteins and tissue fatty acid composition in humans [published correction appears in Lipids 2001 Aug;36(8):857]. Lipids. 2001;36(3):229-236. doi:10.1007/s11745-001-0712-x | Intervention/Exposure; Sample size/Power
194 | Berasategi I, García-Íñiguez de Ciriano M, Navarro-Blasco Í, et al. Reduced-fat bologna sausages with improved lipid fraction. J Sci Food Agric. 2014;94(4):744-751. doi:10.1002/jsfa.6409 | Outcome
195 | Berger A, Rein D, Schäfer A, et al. Similar cholesterol-lowering properties of rice bran oil, with varied gamma-oryzanol, in mildly hypercholesterolemic men. Eur J Nutr. 2005;44(3):163-173. doi:10.1007/s00394-004-0508-9 | Intervention/Exposure
196 | Bergholdt HK, Nordestgaard BG, Varbo A, Ellervik C. Milk intake is not associated with ischaemic heart disease in observational or Mendelian randomization analyses in 98,529 Danish adults. Int J Epidemiol. 2015;44(2):587-603. doi:10.1093/ije/dyv109 | Study design; Comparator
197 | Bergholdt HKM, Nordestgaard BG, Varbo A, Ellervik C. Lactase persistence, milk intake, and mortality in the Danish general population: a Mendelian randomization study. Eur J Epidemiol. 2018;33(2):171-181. doi:10.1007/s10654-017-0328-x | Intervention/Exposure; Comparator
198 | Berglund L, Lefevre M, Ginsberg HN, et al. Comparison of monounsaturated fat with carbohydrates as a replacement for saturated fat in subjects with a high metabolic risk profile: studies in the fasting and postprandial states. Am J Clin Nutr. 2007;86(6):1611-1620. doi:10.1093/ajcn/86.5.1611 | Intervention/Exposure
199 | Berglund L, Oliver EH, Fontanez N, et al. HDL-subpopulation patterns in response to reductions in dietary total and saturated fat intakes in healthy subjects. Am J Clin Nutr. 1999;70(6):992-1000. doi:10.1093/ajcn/70.6.992 | Intervention/Exposure
200 | Berryman CE, West SG, Chen CO, et al. Effects of polyphenolic-rich dark chocolate/cocoa and almonds on established and emerging cardiovascular risk factors: study design. The FASEB Journal. 2013;27(S1). doi:10.1096/fasebj.27.1_supplement.1078.13 | Study design; Publication status
201 | Berthy F, Brunin J, Allès B, et al. Association between adherence to the EAT-Lancet diet and risk of cancer and cardiovascular outcomes in the prospective NutriNet-Santé cohort. Am J Clin Nutr. 2022;116(4):980-991. doi:10.1093/ajcn/nqac208 | Intervention/Exposure
202 | Bertolami MC, Faludi AA, Batlouni M. Evaluation of the effects of a new fermented milk product (Gaio) on primary hypercholesterolemia. Eur J Clin Nutr. 1999;53(2):97-101. doi:10.1038/sj.ejcn.1600683 | Comparator; Sample size/Power
203 | Bethancourt HJ, Kratz M, O’Connor K. A short-term religious “fast" from animal products has a minimal impact on cardiometabolic health biomarkers irrespective of concurrent shifts in distinct plant-based food groups. Am J Clin Nutr. 2019;110(3):722-732. doi:10.1093/ajcn/nqz153 | Intervention/Exposure
204 | Beulen Y, Martínez-González MA, van de Rest O, et al. Quality of Dietary Fat Intake and Body Weight and Obesity in a Mediterranean Population: Secondary Analyses within the PREDIMED Trial. Nutrients. 2018;10(12):2011. Published 2018 Dec 19. doi:10.3390/nu10122011 | Outcome
205 | Beydoun MA, Fanelli-Kuczmarski MT, Beydoun HA, et al. Dairy product consumption and its association with metabolic disturbance in a prospective study of urban adults. Br J Nutr. 2018;119(6):706-719. doi:10.1017/S0007114518000028 | Intervention/Exposure; Comparator
206 | Beydoun MA, Gary TL, Caballero BH, Lawrence RS, Cheskin LJ, Wang Y. Ethnic differences in dairy and related nutrient consumption among US adults and their association with obesity, central obesity, and the metabolic syndrome. Am J Clin Nutr. 2008;87(6):1914-1925. doi:10.1093/ajcn/87.6.1914 | Study design
207 | Bhattacharya R, Zekavat SM, Uddin MM, et al. Association of Diet Quality With Prevalence of Clonal Hematopoiesis and Adverse Cardiovascular Events. JAMA Cardiol. 2021;6(9):1069-1077. doi:10.1001/jamacardio.2021.1678 | Intervention/Exposure
208 | Bhavadharini B, Dehghan M, Mente A, et al. Association of dairy consumption with metabolic syndrome, hypertension and diabetes in 147 812 individuals from 21 countries. BMJ Open Diabetes Res Care. 2020;8(1):e000826. doi:10.1136/bmjdrc-2019-000826 | Comparator
209 | Bianchi F, Stewart C, Astbury NM, Cook B, Aveyard P, Jebb SA. Replacing meat with alternative plant-based products (RE-MAP): a randomized controlled trial of a multicomponent behavioral intervention to reduce meat consumption. Am J Clin Nutr. 2022;115(5):1357-1366. doi:10.1093/ajcn/nqab414 | Intervention/Exposure
210 | Bierenbaum ML, Reichstein RP, Watkins TR, Maginnis WP, Geller M. Effects of canola oil on serum lipids in humans. J Am Coll Nutr. 1991;10(3):228-233. doi:10.1080/07315724.1991.10718149 | Study design; Intervention/Exposure
211 | Biesbroek S, Verschuren WMM, Boer JMA, et al. Does a better adherence to dietary guidelines reduce mortality risk and environmental impact in the Dutch sub-cohort of the European Prospective Investigation into Cancer and Nutrition?. Br J Nutr. 2017;118(1):69-80. doi:10.1017/S0007114517001878 | Intervention/Exposure
212 | Bigornia SJ, Noel SE, Porter C, et al. Red meat consumption, incident CVD and the influence of dietary quality in the Jackson Heart Study. Public Health Nutr. 2023;26(3):643-652. doi:10.1017/S1368980022001434 | Intervention/Exposure; Comparator
213 | Bild DE, Jacobs DR, Liu K, et al. Seven-year trends in plasma low-density-lipoproteincholesterol in young adults: the CARDIA Study. Ann Epidemiol. 1996;6(3):235-245. doi:10.1016/1047-2797(96)00005-1 | Intervention/Exposure
214 | Bilenko N, Fraser D, Vardi H, Shai I, Shahar DR. Mediterranean diet and cardiovascular diseases in an Israeli population. Prev Med. 2005;40(3):299-305. doi:10.1016/j.ypmed.2004.06.004 | Study design
215 | Bingham CM, Lahti-Koski M, Absetz P, et al. Food choices and health during military service: increases in sugar- and fibre-containing foods and changes in anthropometric and clinical risk factors. Public Health Nutr. 2012;15(7):1248-1255. doi:10.1017/S1368980011003351 | Study design; Intervention/Exposure
216 | Biong AS, Müller H, Seljeflot I, Veierød MB, Pedersen JI. A comparison of the effects of cheese and butter on serum lipids, haemostatic variables and homocysteine. Br J Nutr. 2004;92(5):791-797. doi:10.1079/bjn20041257 | Duration
217 | Biong AS, Rebnord HM, Fimreite RL, et al. Intake of dairy fat and dairy products, and risk of myocardial infarction: a case-control study. Int J Food Sci Nutr. 2008;59(2):155-165. doi:10.1080/09637480701532521 | Study design
218 | Bjermo H, Iggman D, Kullberg J, et al. Effects of n-6 PUFAs compared with SFAs on liver fat, lipoproteins, and inflammation in abdominal obesity: a randomized controlled trial. Am J Clin Nutr. 2012;95(5):1003-1012. doi:10.3945/ajcn.111.030114 | Intervention/Exposure; Sample size/Power
219 | Björck L, Rosengren A, Winkvist A, et al. Changes in Dietary Fat Intake and Projections for Coronary Heart Disease Mortality in Sweden: A Simulation Study. PLoS One. 2016. 11:e0160474. doi:10.1371/journal.pone.0160474 | Study design; Intervention/Exposure
220 | Bladbjerg EM, Larsen TM, Due A, Jespersen J, Stender S, Astrup A. Postprandial coagulation activation in overweight individuals after weight loss: acute and long-term effects of a high-monounsaturated fat diet and a low-fat diet. Thromb Res. 2014;133(3):327-333. doi:10.1016/j.thromres.2013.12.010 | Intervention/Exposure; Sample size/Power
221 | Bladbjerg EM, Larsen TM, Due A, Stender S, Astrup A, Jespersen J. Effects on markers of inflammation and endothelial cell function of three ad libitum diets differing in type and amount of fat and carbohydrate: a 6-month randomised study in obese individuals. Br J Nutr. 2011;106(1):123-129. doi:10.1017/S0007114510005829 | Intervention/Exposure
222 | Blankenhorn DH, Johnson RL, Mack WJ, el Zein HA, Vailas LI. The influence of diet on the appearance of new lesions in human coronary arteries. JAMA. 1990;263(12):1646-1652. | Intervention/Exposure; Health status
223 | Blekkenhorst LC, Prince RL, Hodgson JM, et al. Dietary saturated fat intake and atherosclerotic vascular disease mortality in elderly women: a prospective cohort study. Am J Clin Nutr. 2015;101(6):1263-1268. doi:10.3945/ajcn.114.102392 | Intervention/Exposure
224 | Blesso CN, Andersen CJ, Bolling BW, et al. Egg intake improves carotenoid status by increasing plasma HDL cholesterol in adults with metabolic syndrome. Food Funct. 2013. 4:213-21. doi:10.1039/c2fo30154g | Intervention/Exposure
225 | Bo S, Ciccone G, Baldi C, et al. Effectiveness of a lifestyle intervention on metabolic syndrome. A randomized controlled trial. J Gen Intern Med. 2007;22(12):1695-1703. doi:10.1007/s11606-007-0399-6 | Intervention/Exposure
226 | Boden-Albala B, Elkind MS, White H, Szumski A, Paik MC, Sacco RL. Dietary total fat intake and ischemic stroke risk: the Northern Manhattan Study. Neuroepidemiology. 2009;32(4):296-301. doi:10.1159/000204914 | Intervention/Exposure
227 | Bødker M, Pisinger C, Toft U, Jørgensen T. The Danish fat tax-Effects on consumption patterns and risk of ischaemic heart disease. Prev Med. 2015;77:200-203. doi:10.1016/j.ypmed.2015.03.031 | Study design; Intervention/Exposure
228 | Boggs DA, Ban Y, Palmer JR, et al. Higher diet quality is inversely associated with mortality in African-American women. J Nutr. 2015. 145:547-54. doi:10.3945/jn.114.195735 | Intervention/Exposure; Outcome
229 | Bogl LH, Pietiläinen KH, Rissanen A, et al. Association between habitual dietary intake and lipoprotein subclass profile in healthy young adults. Nutr Metab Cardiovasc Dis. 2013;23(11):1071-1078. doi:10.1016/j.numecd.2012.11.007 | Study design; Intervention/Exposure
230 | Bohannon J, Koch D, Homm P, Driehaus A. Chocolate with High Cocoa Content as a Weight-Loss Accelerator. Global Journal of Medical Research. Published online April 24, 2015. https://medicalresearchjournal.org/index.php/GJMR/article/view/922 | Intervention/Exposure; Sample size/Power
231 | Bohl M, Bjørnshave A, Rasmussen KV, et al. Dairy proteins, dairy lipids, and postprandial lipemia in persons with abdominal obesity (DairyHealth): a 12-wk, randomized, parallel-controlled, double-blinded, diet intervention study. Am J Clin Nutr. 2015;101(4):870-878. doi:10.3945/ajcn.114.097923 | Intervention/Exposure; Sample size/Power
232 | Bohl M, Bjørnshave A, Gregersen S, et al. Whey and Casein Proteins and Medium-Chain Saturated Fatty Acids from Milk Do Not Increase Low-Grade Inflammation in Abdominally Obese Adults. Rev Diabet Stud. 2016. 13:148-157. doi:10.1900/rds.2016.13.148 | Intervention/Exposure; Sample size/Power
233 | Bohl M, Bjørnshave A, Larsen MK, et al. The effects of proteins and medium-chain fatty acids from milk on body composition, insulin sensitivity and blood pressure in abdominally obese adults. Eur J Clin Nutr. 2017. 71:76-82. doi:10.1038/ejcn.2016.207 | Intervention/Exposure
234 | Bonaccio M, Di Castelnuovo A, Pounis G, et al. High adherence to the Mediterranean diet is associated with cardiovascular protection in higher but not in lower socioeconomic groups: prospective findings from the Moli-sani study. Int J Epidemiol. 2017;46(5):1478-1487. doi:10.1093/ije/dyx145 | Intervention/Exposure
235 | Bonaccio M, Di Castelnuovo A, Costanzo S, et al. Ultra-processed food consumption is associated with increased risk of all-cause and cardiovascular mortality in the Moli-sani Study. Am J Clin Nutr. 2021. 113:446-455. doi:10.1093/ajcn/nqaa299 | Intervention/Exposure
236 | Bondia-Pons I, Schröder H, Covas MI, et al. Moderate consumption of olive oil by healthy European men reduces systolic blood pressure in non-Mediterranean participants. J Nutr. 2007;137(1):84-87. doi:10.1093/jn/137.1.84 | Duration
237 | Boniface DR, Tefft ME. Dietary fats and 16-year coronary heart disease mortality in a cohort of men and women in Great Britain. [underlined: Eur J Clin Nutr.] 2002. 56:786-92. doi:10.1038/sj.ejcn.1601509 | Intervention/Exposure
238 | Bonthuis M, Hughes MC, Ibiebele TI, et al. Dairy consumption and patterns of mortality of Australian adults. Eur J Clin Nutr. 2010. 64:569-77. doi:10.1038/ejcn.2010.45 | Comparator
239 | Boonyasopun U, Aree P, Avant KC. Effect of an empowerment-based nutrition promotion program on food consumption and serum lipid levels in hyperlipidemic Thai elderly. Nurs Health Sci. 2008;10(2):93-100. doi:10.1111/j.1442-2018.2008.00375.x | Intervention/Exposure
240 | Booth JN 3rd, Colantonio LD, Howard G, et al. Healthy lifestyle factors and incident heart disease and mortality in candidates for primary prevention with statin therapy. Int J Cardiol. 2016;207:196-202. doi:10.1016/j.ijcard.2016.01.001 | Intervention/Exposure
241 | Bork CS, Jakobsen MU, Lundbye-Christensen S, Tjønneland A, Schmidt EB, Overvad K. Dietary intake and adipose tissue content of α-linolenic acid and risk of myocardial infarction: a Danish cohort study. Am J Clin Nutr. 2016;104(1):41-48. doi:10.3945/ajcn.115.127019 | Intervention/Exposure
242 | Bos MB, de Vries JH, Feskens EJ, et al. Effect of a high monounsaturated fatty acids diet and a Mediterranean diet on serum lipids and insulin sensitivity in adults with mild abdominal obesity. Nutr Metab Cardiovasc Dis. 2010. 20:591-8. doi:10.1016/j.numecd.2009.05.008 | Intervention/Exposure; Sample size/Power
243 | Bosaeus M, Hussain A, Karlsson T, et al. A randomized longitudinal dietary intervention study during pregnancy: effects on fish intake, phospholipids, and body composition. Nutr J. 2015. 14:1. doi:10.1186/1475-2891-14-1 | Intervention/Exposure; Outcome
244 | Bosch V, Aular A, Medina J, Ortiz N, Apitz R. Modificaciones de las lipoproteínas del plasma después del uso dietético de la oleína de palma en adultos sanos [Changes in of plasma lipoproteins after the use of palm oil in the diet of a group healthy adults]. Arch Latinoam Nutr. 2002;52(2):145-150. | Publication language
245 | Bostick RM, Kushi LH, Wu Y, Meyer KA, Sellers TA, Folsom AR. Relation of calcium, vitamin D, and dairy food intake to ischemic heart disease mortality among postmenopausal women. Am J Epidemiol. 1999;149(2):151-161. doi:10.1093/oxfordjournals.aje.a009781 | Intervention/Exposure; Comparator
246 | Bouziotas C, Koutedakis Y. A Three Year Study of Coronary Heart Disease Risk Factors in Greek Adolescents. Pediatric Exercise Science. 2003;15(1):9-18. doi:https://doi.org/10.1123/pes.15.1. | Intervention/Exposure
247 | Bovalino S, Charleson G, Szoeke C. The impact of red and processed meat consumption on cardiovascular disease risk in women. Nutrition. 2016;32(3):349-354. doi:10.1016/j.nut.2015.09.015 | Outcome
248 | Bowen KJ, Kris-Etherton PM, West SG, et al. Diets Enriched with Conventional or High-Oleic Acid Canola Oils Lower Atherogenic Lipids and Lipoproteins Compared to a Diet with a Western Fatty Acid Profile in Adults with Central Adiposity. J Nutr. 2019;149(3):471-478. doi:10.1093/jn/nxy307 | Intervention/Exposure; Comparator
249 | Bowen J, Noakes M, Clifton PM. Effect of calcium and dairy foods in high protein, energy-restricted diets on weight loss and metabolic parameters in overweight adults. Int J Obes (Lond). 2005. 29:957-65. doi:10.1038/sj.ijo.0802895 | Intervention/Exposure; Comparator
250 | Brace LD, Gittler-Buffa C, Miller GJ, et al. Factor VII coagulant activity and cholesterol changes in premenopausal women consuming a long-term cholesterol-lowering diet. Arterioscler Thromb. 1994;14(8):1284-1289. doi:10.1161/01.atv.14.8.1284 | Intervention/Exposure; Sample size/Power
251 | Bradlee ML, Singer MR, Daniels SR, Moore LL. Eating patterns and lipid levels in older adolescent girls. Nutr Metab Cardiovasc Dis. 2013;23(3):196-204. doi:10.1016/j.numecd.2011.10.010 | Intervention/Exposure; Comparator
252 | Bradlee ML, Singer MR, Moore LL. Lean red meat consumption and lipid profiles in adolescent girls. J Hum Nutr Diet. 2014;27 Suppl 2(0 2):292-300. doi:10.1111/jhn.12106 | Comparator
253 | Bradley U, Spence M, Courtney CH, et al. Low-fat versus low-carbohydrate weight reduction diets: effects on weight loss, insulin resistance, and cardiovascular risk: a randomized control trial. Diabetes. 2009;58(12):2741-2748. doi:10.2337/db09-0098 | Intervention/Exposure
254 | Brassard D, Arsenault BJ, Boyer M, et al. Saturated Fats from Butter but Not from Cheese Increase HDL-Mediated Cholesterol Efflux Capacity from J774 Macrophages in Men and Women with Abdominal Obesity. J Nutr. 2018. 148:573-580. doi:10.1093/jn/nxy014 | Data overlap
255 | Bray GA, Lovejoy JC, Most-Windhauser M, et al. A 9-mo randomized clinical trial comparing fat-substituted and fat-reduced diets in healthy obese men: the Ole Study. Am J Clin Nutr. 2002;76(5):928-934. doi:10.1093/ajcn/76.5.928 | Intervention/Exposure; Sample size/Power
256 | Bray GA, Vollmer WM, Sacks FM, et al. A further subgroup analysis of the effects of the DASH diet and three dietary sodium levels on blood pressure: results of the DASH-Sodium Trial [published correction appears in Am J Cardiol. 2010 Feb 15;105(4):579]. Am J Cardiol. 2004;94(2):222-227. doi:10.1016/j.amjcard.2004.03.070 | Intervention/Exposure
257 | Brayner B, Keske MA, Kaur G, et al. Longitudinal Associations Between Fat-Derived Dietary Patterns and Early Markers of Cardiovascular Disease Risk in the UK Biobank Study. J Am Heart Assoc. 2022. 11:e024069. doi:10.1161/jaha.121.024069 | Intervention/Exposure
258 | Brekke HK, Jansson PA, Lenner RA. Long-term (1- and 2-year) effects of lifestyle intervention in type 2 diabetes relatives. Diabetes Res Clin Pract. 2005;70(3):225-234. doi:10.1016/j.diabres.2005.03.027 | Intervention/Exposure
259 | Bricarello LP, Kasinski N, Bertolami MC, et al. Comparison between the effects of soy milk and non-fat cow milk on lipid profile and lipid peroxidation in patients with primary hypercholesterolemia. Nutrition. 2004;20(2):200-204. doi:10.1016/j.nut.2003.10.005 | Intervention/Exposure
260 | Brinkworth GD, Noakes M, Buckley JD, Keogh JB, Clifton PM. Long-term effects of a very-low-carbohydrate weight loss diet compared with an isocaloric low-fat diet after 12 mo. Am J Clin Nutr. 2009;90(1):23-32. doi:10.3945/ajcn.2008.27326 | Intervention/Exposure
261 | Brinton EA, Eisenberg S, Breslow JL. A low-fat diet decreases high density lipoprotein (HDL) cholesterol levels by decreasing HDL apolipoprotein transport rates. J Clin Invest. 1990;85(1):144-151. doi:10.1172/JCI114405 | Intervention/Exposure
262 | Brown AW, Trenkle AH, Beitz DC. Diets high in conjugated linoleic acid from pasture-fed cattle did not alter markers of health in young women. Nutr Res. 2011;31(1):33-41. doi:10.1016/j.nutres.2010.12.003 | Intervention/Exposure; Comparator
263 | Brown RC, Cox CM. Effects of high fat versus high carbohydrate diets on plasma lipids and lipoproteins in endurance athletes. Med Sci Sports Exerc. 1998;30(12):1677-1683. doi:10.1097/00005768-199812000-00004 | Intervention/Exposure
264 | Brox J, Bjørnstad E, Olaussen K, et al. Blood lipids, fatty acids, diet and lifestyle parameters in adolescents from a region in northern Norway with a high mortality from coronary heart disease. Eur J Clin Nutr. 2002. 56:694-700. doi:10.1038/sj.ejcn.1601381 | Intervention/Exposure
265 | Bruce B, Spiller GA, Klevay LM, Gallagher SK. A diet high in whole and unrefined foods favorably alters lipids, antioxidant defenses, and colon function. J Am Coll Nutr. 2000;19(1):61-67. doi:10.1080/07315724.2000.10718915 | Intervention/Exposure; Sample size/Power
266 | Brunner EJ, Mosdøl A, Witte DR, et al. Dietary patterns and 15-y risks of major coronary events, diabetes, and mortality. Am J Clin Nutr. 2008;87(5):1414-1421. doi:10.1093/ajcn/87.5.1414 | Intervention/Exposure
267 | Bruno E, Manoukian S, Venturelli E, et al. Adherence to Mediterranean Diet and Metabolic Syndrome in BRCA Mutation Carriers. Integrative Cancer Therapies. 2018. 17:153-160. doi:10.1177/1534735417721015 | Intervention/Exposure
268 | Bub A, Malpuech-Brugère C, Orfila C, et al. A Dietary Intervention of Bioactive Enriched Foods Aimed at Adults at Risk of Metabolic Syndrome: Protocol and Results from PATHWAY-27 Pilot Study. Nutrients. 2019;11(8):1814. Published 2019 Aug 6. doi:10.3390/nu11081814 | Intervention/Exposure
269 | Bubeck AM, Urbain P, Horn C, et al. High-fat diet impact on intestinal cholesterol conversion by the microbiota and serum cholesterol levels. iScience. 2023;26(9):107697. doi:10.1016/j.isci.2023.107697 | Intervention/Exposure
270 | Budhathoki S, Sawada N, Iwasaki M, et al. Association of Animal and Plant Protein Intake With All-Cause and Cause-Specific Mortality in a Japanese Cohort [published correction appears in JAMA Intern Med. 2019 Oct 1;179(10):1448. doi: 10.1001/jamainternmed.2019.4883]. JAMA Intern Med. 2019;179(11):1509-1518. doi:10.1001/jamainternmed.2019.2806 | Intervention/Exposure
271 | Buendia JR, Li Y, Hu, FB, et al. Long-term yogurt consumption and risk of incident hypertension in adults. J Hypertens. 2018. 36:1671-1679. doi:10.1097/hjh.0000000000001737 | Comparator
272 | Buendia JR, Li Y, Hu FB, et al. Regular Yogurt Intake and Risk of Cardiovascular Disease Among Hypertensive Adults. Am J Hypertens. 2018. 31:557-565. doi:10.1093/ajh/hpx220 | Comparator
273 | Buijsse B, Weikert C, Drogan D, Bergmann M, Boeing H. Chocolate consumption in relation to blood pressure and risk of cardiovascular disease in German adults. Eur Heart J. 2010;31(13):1616-1623. doi:10.1093/eurheartj/ehq068 | Comparator
274 | Bukhari AS, Lutz LJ, Smith TJ, et al. A Food-Based Intervention in a Military Dining Facility Improves Blood Fatty Acid Profile. Nutrients. 2022;14(4):743. Published 2022 Feb 10. doi:10.3390/nu14040743 | Intervention/Exposure
275 | Bunyard LB, Dennis KE, Nicklas BJ. Dietary intake and changes in lipoprotein lipids in obese, postmenopausal women placed on an American Heart Association Step 1 diet. J Am Diet Assoc. 2002;102(1):52-57. doi:10.1016/s0002-8223(02)90016-7 | Intervention/Exposure
276 | Buonacorso V, Nakandakare ER, Nunes VS, Passarelli M, Quintão EC, Lottenberg AM. Macrophage cholesterol efflux elicited by human total plasma and by HDL subfractions is not affected by different types of dietary fatty acids. Am J Clin Nutr. 2007;86(5):1270-1277. doi:10.1093/ajcn/86.5.1270 | Sample size/Power
277 | Buonopane GJ, Kilara A, Smith JS, McCarthy RD. Effect of skim milk supplementation on blood cholesterol concentration, blood pressure, and triglycerides in a free-living human population. J Am Coll Nutr. 1992;11(1):56-67. doi:10.1080/07315724.1992.10718197 | Study design; Intervention/Exposure; Comparator
278 | Burdge GC, Finnegan YE, Minihane AM, Williams CM, Wootton SA. Effect of altered dietary n-3 fatty acid intake upon plasma lipid fatty acid composition, conversion of [13C]alpha-linolenic acid to longer-chain fatty acids and partitioning towards beta-oxidation in older men. Br J Nutr. 2003;90(2):311-321. doi:10.1079/bjn2003901 | Intervention/Exposure
279 | Burdge GC, Tricon S, Morgan R, et al. Incorporation of cis-9, trans-11 conjugated linoleic acid and vaccenic acid (trans-11 18 : 1) into plasma and leucocyte lipids in healthy men consuming dairy products naturally enriched in these fatty acids. Br J Nutr. 2005. 94:237-43. doi:10.1079/bjn20051506 | Intervention/Exposure; Outcome; Comparator
280 | Burén J, Ericsson M, Damasceno NRT, Sjödin A. A Ketogenic Low-Carbohydrate High-Fat Diet Increases LDL Cholesterol in Healthy, Young, Normal-Weight Women: A Randomized Controlled Feeding Trial. Nutrients. 2021;13(3):814. Published 2021 Mar 2. doi:10.3390/nu13030814 | Intervention/Exposure
281 | Burke LE, Dunbar-Jacob J, Orchard TJ, Sereika SM. Improving adherence to a cholesterol-lowering diet: a behavioral intervention study. Patient Educ Couns. 2005;57(1):134-142. doi:10.1016/j.pec.2004.05.007 | Intervention/Exposure
282 | Burke LE, Dunbar-Jacob J, Orchard TJ, Sereika SM. Improving adherence to a cholesterol-lowering diet: a behavioral intervention study. Patient Educ Couns. 2005;57(1):134-142. doi:10.1016/j.pec.2004.05.007 | Intervention/Exposure
283 | Burke LE, Hudson AG, Warziski MT, et al. Effects of a vegetarian diet and treatment preference on biochemical and dietary variables in overweight and obese adults: a randomized clinical trial. Am J Clin Nutr. 2007;86(3):588-596. doi:10.1093/ajcn/86.3.588 | Intervention/Exposure
284 | Burke LE, Styn MA, Steenkiste AR, Music E, Warziski M, Choo J. A randomized clinical trial testing treatment preference and two dietary options in behavioral weight management: preliminary results of the impact of diet at 6 months-PREFER study. Obesity (Silver Spring). 2006;14(11):2007-2017. doi:10.1038/oby.2006.235 | Intervention/Exposure
285 | Burke V, Mansour J, Beilin LJ, Mori TA. Long-term follow-up of participants in a health promotion program for treated hypertensives (ADAPT). Nutr Metab Cardiovasc Dis. 2008;18(3):198-206. doi:10.1016/j.numecd.2006.10.004 | Intervention/Exposure
286 | Burke V, Zhao Y, Lee AH, et al. Health-related behaviours as predictors of mortality and morbidity in Australian Aborigines. Prev Med. 2007;44(2):135-142. doi:10.1016/j.ypmed.2006.09.008 | Intervention/Exposure
287 | Burns-Whitmore B, Haddad E, Sabaté J, Rajaram S. Effects of supplementing n-3 fatty acid enriched eggs and walnuts on cardiovascular disease risk markers in healthy free-living lacto-ovo-vegetarians: a randomized, crossover, free-living intervention study. Nutr J. 2014;13:29. Published 2014 Mar 27. doi:10.1186/1475-2891-13-29 | Intervention/Exposure
288 | Burr ML, Dunstan FD, George CH. Is fish oil good or bad for heart disease? Two trials with apparently conflicting results. J Membr Biol. 2005;206(2):155-163. doi:10.1007/s00232-005-0784-1 | Intervention/Exposure
289 | Burr ML, Fehily AM. Fatty fish and heart disease: a randomized controlled trial. World Rev Nutr Diet. 1991;66:306-312. doi:10.1159/000419300 | Study design; Intervention/Exposure
290 | Buscemi S, Corleo D, Buscemi C, et al. Influence of Habitual Dairy Food Intake on LDL Cholesterol in a Population-Based Cohort. Nutrients. 2021;13(2):593. Published 2021 Feb 11. doi:10.3390/nu13020593 | Study design
291 | Buscemi S, Verga S, Tranchina MR, Cottone S, Cerasola G. Effects of hypocaloric very-low-carbohydrate diet vs. Mediterranean diet on endothelial function in obese women*. Eur J Clin Invest. 2009;39(5):339-347. doi:10.1111/j.1365-2362.2009.02091.x | Intervention/Exposure
292 | Buyken AE, Flood V, Rochtchina E, Nestel P, Brand-Miller J, Mitchell P. Modifications in dietary fat quality are associated with changes in serum lipids of older adults independently of lipid medication. J Nutr. 2010;140(1):88-94. doi:10.3945/jn.109.110486 | Intervention/Exposure; Comparator
293 | Buyuktuncer Z, Fisunoğlu M, Guven GS, Unal S, Besler HT. The cholesterol lowering efficacy of plant stanol ester yoghurt in a Turkish population: a double-blind, placebo-controlled trial. Lipids Health Dis. 2013;12:91. Published 2013 Jun 20. doi:10.1186/1476-511X-12-91 | Comparator
294 | Buziau AM, Soedamah-Muthu SS, Geleijnse JM, Mishra GD. Total Fermented Dairy Food Intake Is Inversely Associated with Cardiovascular Disease Risk in Women. J Nutr. 2019;149(10):1797-1804. doi:10.1093/jn/nxz128 | Intervention/Exposure; Comparator
295 | Cahill LE, Pan A, Chiuve SE, et al. Fried-food consumption and risk of type 2 diabetes and coronary artery disease: a prospective study in 2 cohorts of US women and men. Am J Clin Nutr. 2014;100(2):667-675. doi:10.3945/ajcn.114.084129 | Intervention/Exposure
296 | Cai, H, Shu, XO, Gao, YT, et al. A prospective study of dietary patterns and mortality in Chinese women. Epidemiology. 2007. 18:393-401. doi:10.1097/01.ede.0000259967.21114.45 | Intervention/Exposure; Country
297 | Calandre, L, Diaz-Guzman, J, Ferrero, M, et al. Risk factors, diet and carotid atheromatosis in TIAs and minor ischemic strokes (MISs) in a Mediterranean country. Eur J Neurol. Sep 1995;2(4):325-30. doi:10.1111/j.1468-1331.1995.tb00134.x | Intervention/Exposure
298 | Calder, PC. Lipids: A hole in the diet-heart hypothesis? Nat Rev Cardiol. Jul 2016;13(7):385-6. doi:10.1038/nrcardio.2016.78 | Study design
299 | Callahan, E. Changes in weight loss and lipid profiles after a dietary purification program: a prospective case series. J Chiropr Med. 2013. 12:30-8. doi:10.1016/j.jcm.2012.11.004 | Intervention/Exposure; Duration
300 | Camargo, A, Meneses, ME, Perez-Martinez, P, et al. Dietary fat differentially influences the lipids storage on the adipose tissue in metabolic syndrome patients. Eur J Nutr. 2014;53(2):617-26. doi:10.1007/s00394-013-0570-2 | Intervention/Exposure; Sample size/Power
301 | Camargo, A, Meneses, ME, Pérez-Martínez, P, et al. Dietary fat modifies lipid metabolism in the adipose tissue of metabolic syndrome patients. Genes Nutr. Jul 2014;9(4):409. doi:10.1007/s12263-014-0409-3 | Intervention/Exposure; Outcome
302 | Camhi SM, Stefanick ML, Ridker PM, Young DR. Changes in C-reactive protein from low-fat diet and/or physical activity in men and women with and without metabolic syndrome. Metabolism. 2010;59(1):54-61. doi:10.1016/j.metabol.2009.07.008 | Intervention/Exposure
303 | Camhi, SM, Crouter, SE, Hayman, LL, et al. Lifestyle Behaviors in Metabolically Healthy and Unhealthy Overweight and Obese Women: A Preliminary Study. PLoS One. 2015. 10:e0138548. doi:10.1371/journal.pone.0138548 | Study design; Outcome
304 | Campbell W, Davis E, Bergia R, Hartman A, Landberg R, Riccardi G. P14-009-23 Impact of Dinner Meat Sources on Changes in Cardiovascular Disease Risk Factors With a Mediterranean Diet: Secondary Analysis From a Randomized Controlled Trial. Current Developments in Nutrition. 2023;7:100623. doi:10.1016/j.cdnut.2023.100623 | Publication status
305 | Campbell, EK, Fidahusain, M, Campbell Ii, TM. Evaluation of an Eight-Week Whole-Food Plant-Based Lifestyle Modification Program. Nutrients. Sep 3 2019;11(9)doi:10.3390/nu11092068 | Intervention/Exposure
306 | Canales, A, Bastida, S, Librelottto, J, et al. Platelet aggregation, eicosanoid production and thrombogenic ratio in individuals at high cardiovascular risk consuming meat enriched in walnut paste. A crossover, placebo-controlled study. Br J Nutr. 2009. 102:134-41. doi:10.1017/s000711450813361x | Intervention/Exposure; Outcome; Comparator
307 | Canales, A, Benedi, J, Bastida, S, et al. The effect of consuming meat enriched in walnut paste on platelet aggregation and thrombogenesis varies in volunteers with different apolipoprotein A4 genotype. Nutr Hosp. Sep-Oct 2010;25(5):746-54. | Outcome; Comparator
308 | Canales, A, Benedí, J, Nus, M, et al. Effect of walnut-enriched restructured meat in the antioxidant status of overweight/obese senior subjects with at least one extra CHD-risk factor. Journal of the American College of Nutrition. Jun 2007;26(3):225-232. doi:Doi 10.1080/07315724.2007.10719605 | Sample size/Power
309 | Cano-Ibáñez, N, Quintana-Navarro, GM, Alcala-Diaz, JF, et al. Long-term effect of a dietary intervention with two-healthy dietary approaches on food intake and nutrient density in coronary patients: results from the CORDIOPREV trial. Eur J Nutr. 2022. 61:3019-3036. doi:10.1007/s00394-022-02854-7 | Health status
310 | Capra, ME, Pederiva, C, Viggiano, C, et al. Nutritional Treatment in a Cohort of Pediatric Patients with Familial Hypercholesterolaemia: Effect on Lipid Profile. Nutrients. 2022. 14:2817. doi:10.3390/nu14142817 | Study design; Intervention/Exposure
311 | Carballo-Casla A, Stefler D, Ortolá R, et al. The Southern European Atlantic diet and all-cause and cause-specific mortality: a European multicohort study. Eur J Prev Cardiol. 2024;31(3):358-367. doi:10.1093/eurjpc/zwad370 | Comparator
312 | Carballo-Casla, A, Ortolá, R, García-Esquinas, E, et al. The Southern European Atlantic Diet and all-cause mortality in older adults. BMC Med. 2021. 19:36. doi:10.1186/s12916-021-01911-y | Intervention/Exposure; Outcome
313 | Cardona-Ocampo, MC, Giraldo-Restrepo, ML, Angarita-Fuentes, LA, et al. Declared and calculated adherence to chocolate consumption in the participants of a clinical trial that measures the effect of cocoa on arterial hypertension with recent diagnosis. Medellin, Colombia. Iatreia. Oct-Dec 2019;32(4):354-357. doi:10.17533/udea.iatreia.17 | Publication language
314 | Cardoso, DA, Moreira, AS, de Oliveira, GM, et al. A COCONUT EXTRA VIRGIN OIL-RICH DIET INCREASES HDL CHOLESTEROL AND DECREASES WAIST CIRCUMFERENCE AND BODY MASS IN CORONARY ARTERY DISEASE PATIENTS. Nutr Hosp. 2015. 32:2144-52. doi:10.3305/nh.2015.32.5.9642 | Health status; Sample size/Power
315 | Carlsson, AC, Wändell, PE, Gigante, B, et al. Seven modifiable lifestyle factors predict reduced risk for ischemic cardiovascular disease and all-cause mortality regardless of body mass index: a cohort study. Int J Cardiol. Sep 30 2013;168(2):94652. doi:10.1016/j.ijcard.2012.10.045 | Intervention/Exposure
316 | Carnethon, MR, Loria, CM, Hill, JO, et al. Risk factors for the metabolic syndrome: the Coronary Artery Risk Development in Young Adults (CARDIA) study, 1985-2001. Diabetes Care. Nov 2004;27(11):2707-15. doi:10.2337/diacare.27.11.2707 | Intervention/Exposure; Outcome
317 | Carr, PR, Jansen, L, Walter, V, et al. Associations of red and processed meat with survival after colorectal cancer and differences according to timing of dietary assessment. Am J Clin Nutr. 2016. 103:192-200. doi:10.3945/ajcn.115.121145 | Health status; Outcome
318 | Carranza J, M. Alvizouri, Á. Rodríguez, Campos Y, Nieto VF. Lower quantities of avocado as daily source of monounsaturated fats: Effect on serum and membrane lipids, endothelial function, platelet aggregation and C-reactive protein in patients with metabolic syndrome. Medicina Interna de México. 2004;20(6):409-424. | Intervention/Exposure; Publication language; Sample size/Power
319 | Carrero, JJ, Baró, L, Fonollá, J, et al. Cardiovascular effects of milk enriched with omega-3 polyunsaturated fatty acids, oleic acid, folic acid, and vitamins E and B6 in volunteers with mild hyperlipidemia. Nutrition. 2004. 20:521-7. doi:10.1016/j.nut.2004.03.017 | Comparator; Sample size/Power
320 | Carrero, JJ, Fonollá, J, Marti, JL, et al. Intake of fish oil, oleic acid, folic acid, and vitamins B-6 and E for 1 year decreases plasma C-reactive protein and reduces coronary heart disease risk factors in male patients in a cardiac rehabilitation program. J Nutr. 2007. 137:384-90. doi:10.1093/jn/137.2.384 | Intervention/Exposure; Health status
321 | Carrizo, D, Chevallier, OP, Woodside, JV, et al. Untargeted metabolomic analysis of human serum samples associated with different levels of red meat consumption: A possible indicator of type 2 diabetes?. Food Chem. 2017. 221:214-221. doi:10.1016/j.foodchem.2016.10.056 | Study design; Outcome
322 | Carroll, AE, Doherty, TS. Meat Consumption and Health: Food for Thought. Ann Intern Med. Nov 19 2019;171(10):767-768. doi:10.7326/M19-2620 | Study design; Publication status
323 | Carson, JA, Michalsky, L, Latson, B, et al. The cardiovascular health of urban African Americans: diet-related results from the Genes, Nutrition, Exercise, Wellness, and Spiritual Growth (GoodNEWS) trial. J Acad Nutr Diet. Nov 2012;112(11):1852-8. doi:10.1016/j.jand.2012.06.357 | Intervention/Exposure
324 | Casas-Agustench, P, Serra, M, Pérez-Heras, A, et al. Effects of plant sterol esters in skimmed milk and vegetable-fat-enriched milk on serum lipids and non-cholesterol sterols in hypercholesterolaemic subjects: a randomised, placebo-controlled, crossover study. Br J Nutr. 2012. 107:1766-75. doi:10.1017/s0007114511005162 | Intervention/Exposure; Comparator
325 | Casiglia, E, Semplicini, A, Businaro, R, et al. Effects of Medium-Term Soybean Treatment on Lipid Pattern and Hemodynamics. Advances in Therapy. Mar-Apr 1991;8(2):78-85. | Intervention/Exposure
326 | Cassady, BA, Charboneau, NL, Brys, EE, et al. Effects of low carbohydrate diets high in red meats or poultry, fish and shellfish on plasma lipids and weight loss. Nutr Metab (Lond). 2007. 4:23. doi:10.1186/1743-7075-4-23 | Sample size/Power
327 | Castellana, F, Zupo, R, Bortone, I, et al. Traditional Old Dietary Pattern of Castellana Grotte (Apulia) Is Associated with Healthy Outcomes. Nutrients. Oct 12 2020;12(10)doi:10.3390/nu12103097 | Comparator
328 | Cater, NB, Heller, HJ, Denke, MA. Comparison of the effects of medium-chain triacylglycerols, palm oil, and high oleic acid sunflower oil on plasma triacylglycerol fatty acids and lipid and lipoprotein concentrations in humans. Am J Clin Nutr. Jan 1997;65(1):41-5. doi:10.1093/ajcn/65.1.41 | Intervention/Exposure; Sample size/Power
329 | Celada, P, Delgado-Pando, G, Olmedilla-Alonso, B, et al. IMPACT OF IMPROVED FAT-MEAT PRODUCTS CONSUMPTION ON ANTHROPOMETRIC MARKERS AND NUTRIENT INTAKES OF MALE VOLUNTEERS AT INCREASED CARDIOVASCULAR RISK. Nutr Hosp. 2015. 32:710-21. doi:10.3305/nh.2015.32.2.9231 | Outcome; Sample size/Power
330 | Celada, P, Sánchez-Muniz, FJ, Delgado-Pando, G, et al. Effects of improved fat meat products consumption on emergent cardiovascular disease markers of male volunteers at cardiovascular risk. J Physiol Biochem. 2016. 72:669-678. doi:10.1007/s13105-016-0505-5 | Outcome; Sample size/Power
331 | Celik, N, Inanc, N. Effects of dairy products consumption on weight loss and blood chemistry in premenopausal obese women. J Pak Med Assoc. Jan 2016;66(1):76-82. | Sample size/Power
332 | Cha, D, Park, Y. Association between Dietary Cholesterol and Their Food Sources and Risk for Hypercholesterolemia: The 2012⁻2016 Korea National Health and Nutrition Examination Survey. Nutrients. 2019. 11:846. doi:10.3390/nu11040846 | Study design
333 | Chamorro, R, Farías, R, Allende, P, et al. Effect of a pescetarian and vegan diet on fatty acid composition in blood and spermatozoa in young healthy men. Prostaglandins Leukot Essent Fatty Acids. Sep 2023;196:102582. doi:10.1016/j.plefa.2023.102582 | Intervention/Exposure
334 | Chan, EK, Quach, J, Mensah, FK, et al. Dark chocolate for children’s blood pressure: randomised trial. Arch Dis Child. Jul 2012;97(7):637-40. doi:10.1136/archdischild-2011-301305 | Intervention/Exposure; Comparator
335 | Chan, R, Chan, D, Woo, J. The association of a priori and a posterior dietary patterns with the risk of incident stroke in Chinese older people in Hong Kong. J Nutr Health Aging. 2013;17(10):866-74. doi:10.1007/s12603-013-0334-y | Intervention/Exposure
336 | Chan, RSM, Yu, BWM, Leung, J, et al. How Dietary Patterns are Related to Inflammaging and Mortality in Community-Dwelling Older Chinese Adults in Hong Kong A Prospective Analysis. Journal of Nutrition Health & Aging. Feb 2019;23(2):181-194. doi:10.1007/s12603-018-1143-0 | Intervention/Exposure
337 | Chang, BJ, Park, SU, Jang, YS, et al. Effect of functional yogurt NY-YP901 in improving the trait of metabolic syndrome. Eur J Clin Nutr. 2011. 65:1250-5. doi:10.1038/ejcn.2011.115 | Comparator
338 | Chang, LF, Vethakkan, SR, Nesaretnam, K, et al. Adverse effects on insulin secretion of replacing saturated fat with refined carbohydrate but not with monounsaturated fat: A randomized controlled trial in centrally obese subjects. J Clin Lipidol. Nov-Dec 2016;10(6):1431-1441 e1. doi:10.1016/j.jacl.2016.09.006 | Intervention/Exposure
339 | Chang, SH, Chang, YY, Jeng, WJ, et al. Efficacy of a multidimensional self-management intervention on low-education women with metabolic syndrome: a cluster randomized controlled trial. Sci Rep. 2023. 13:10358. doi:10.1038/s41598-023-36971-y | Intervention/Exposure
340 | Chang-Claude, J, Hermann, S, Eilber, U, et al. Lifestyle determinants and mortality in German vegetarians and health-conscious persons: results of a 21-year follow-up. Cancer Epidemiol Biomarkers Prev. 2005. 14:963-8. doi:10.1158/1055-9965.Epi-04-0696 | Intervention/Exposure; Comparator
341 | Changwei, L, Bundy, JD, Tian, L, et al. Examination of Serum Metabolome Altered by Dietary Carbohydrate, Milk Protein, and Soy Protein Interventions Identified Novel Metabolites Associated with Blood Pressure: The ProBP Trial. Article in Press. Mol Nutr Food Res. Oct 2023;67(20):e2300044. doi:10.1002/mnfr.202300044 | Intervention/Exposure; Sample size/Power
342 | Charest, A, Vanstone, C, St-Onge, MP, et al. Phytosterols in nonfat and low-fat beverages have no impact on the LDL size phenotype. Eur J Clin Nutr. 2005. 59:801-4. doi:10.1038/sj.ejcn.1602142 | Sample size/Power
343 | Charles, MA, Fontbonne, A, Thibult, N, et al. High plasma nonesterified fatty acids are predictive of cancer mortality but not of coronary heart disease mortality: results from the Paris Prospective Study. Am J Epidemiol. Feb 1 2001;153(3):292-8. doi:10.1093/aje/153.3.292 | Intervention/Exposure
344 | Charlton, KE, Steyn, K, Levitt, NS, et al. A food-based dietary strategy lowers blood pressure in a low socio-economic setting: a randomised study in South Africa. Public Health Nutr. 2008. 11:1397-406. doi:10.1017/s136898000800342x | Intervention/Exposure; Country
345 | Chen X, Hou C, Yao L, et al. Dietary inflammation index is associated with dyslipidemia: evidence from national health and nutrition examination survey, 1999-2019. Lipids Health Dis. 2023;22(1):149. Published 2023 Sep 9. doi:10.1186/s12944-023-01914-z | Intervention/Exposure; Outcome
346 | Chen, CG, Wang, P, Zhang, ZQ, et al. Effects of plant oils with different fatty acid composition on cardiovascular risk factors in moderately hypercholesteremic Chinese adults: a randomized, double-blinded, parallel-designed trial. Food Funct. 2020. 11:7164-7174. doi:10.1039/d0fo00875c | Country
347 | Chen, F, Hu, W, Chen, S, et al. Stroke mortality attributable to high red meat intake in China and South Korea: An age-period-cohort and joinpoint analysis. Front Nutr. 2022. 9:921592. doi:10.3389/fnut.2022.921592 | Study design
348 | Chen, GC, Arthur, R, Mossavar-Rahmani, Y, et al. Adherence to Recommended Eating Patterns Is Associated With Lower Risk of Peripheral Arterial Disease: Results From the Women’s Health Initiative. Hypertension. Aug 2021;78(2):447-455. doi:10.1161/Hypertensionaha.121.17432 | Comparator
349 | Chen, GC, Chen, LH, Mossavar-Rahmani, Y, et al. Dietary cholesterol and egg intake in relation to incident cardiovascular disease and all-cause and cause-specific mortality in postmenopausal women. Am J Clin Nutr. 2021. 113:948-959. doi:10.1093/ajcn/nqaa353 | Intervention/Exposure
350 | Chen, JR, Hsu, SF, Hsu, CD, et al. Dietary patterns and blood fatty acid composition in children with attention-deficit hyperactivity disorder in Taiwan. J Nutr Biochem. 2004. 15:467-72. doi:10.1016/j.jnutbio.2004.01.008 | Study design; Health status
351 | Chen, M, Li, Y, Sun, Q, et al. Dairy fat and risk of cardiovascular disease in 3 cohorts of US adults. Am J Clin Nutr. 2016. 104:1209-1217. doi:10.3945/ajcn.116.134460 | Intervention/Exposure
352 | Chen, Q, Turban, S, Miller, ER, et al. The effects of dietary patterns on plasma renin activity: results from the Dietary Approaches to Stop Hypertension trial. J Hum Hypertens. Nov 2012;26(11):664-9. doi:10.1038/jhh.2011.87 | Intervention/Exposure
353 | Chen, ST, Ferng, SH, Yang, CS, et al. Variable effects of soy protein on plasma lipids in hyperlipidemic and normolipidemic hemodialysis patients. Am J Kidney Dis. Dec 2005;46(6):1099-106. doi:10.1053/j.ajkd.2005.08.031 | Health status
354 | Chen, ST, Maruthur, NM, Appel, LJ. The effect of dietary patterns on estimated coronary heart disease risk: results from the Dietary Approaches to Stop Hypertension (DASH) trial. Circ Cardiovasc Qual Outcomes. 2010. 3:484-9. doi:10.1161/circoutcomes.109.930685 | Intervention/Exposure
355 | Chen, Y, Feng, R, Yang, X, et al. Yogurt improves insulin resistance and liver fat in obese women with nonalcoholic fatty liver disease and metabolic syndrome: A randomized controlled trial. American Journal of Clinical Nutrition. 2019. 109:1611-1619. doi:10.1093/ajcn/nqy358 | Health status
356 | Cheraghi, Z, Mirmiran, P, Mansournia, MA, et al. The association between nutritional exposures and metabolic syndrome in the Tehran Lipid and Glucose Study (TLGS): a cohort study. Public Health. Nov 2016;140:163-171. doi:10.1016/j.puhe.2016.07.003 | Intervention/Exposure; Outcome
357 | Cheung, MC, Lichtenstein, AH, Schaefer, EJ. Effects of a diet restricted in saturated fatty acids and cholesterol on the composition of apolipoprotein A-I-containing lipoprotein particles in the fasting and fed states. Am J Clin Nutr. Dec 1994;60(6):911-8. doi:10.1093/ajcn/60.6.911 | Intervention/Exposure; Sample size/Power
358 | Chi, D, Nakano, M, Yamamoto, K. Milk and milk products consumption in relationship to serum lipid levels: a community-based study of middle-aged and older population in Japan. Cent Eur J Public Health. Jun 2004;12(2):84-7. | Study design
359 | Chien, KL, Lin, HJ, Hsu, HC, et al. Comparison of predictive performance of various fatty acids for the risk of cardiovascular disease events and all-cause deaths in a community-based cohort. Atherosclerosis. Sep 2013;230(1):140-147. doi:10.1016/j.atherosclerosis.2013.06.015 | Intervention/Exposure
360 | Childs MT, King IB, Knopp RH. Divergent lipoprotein responses to fish oils with various ratios of eicosapentaenoic acid and docosahexaenoic acid. Am J Clin Nutr. 1990;52(4):632-639. doi:10.1093/ajcn/52.4.632 | Sample size/Power
361 | Chima, CS, Miller-Kovach, K, Zeller, M, et al. Lipid management clinic: dietary intervention for patients with hypercholesterolemia. J Am Diet Assoc. Feb 1990;90(2):272-4. | Intervention/Exposure
362 | Chisholm A, Mann J, Sutherland W, Duncan A, Skeaff M, Frampton C. Effect on lipoprotein profile of replacing butter with margarine in a low fat diet: randomised crossover study with hypercholesterolaemic subjects [published correction appears in BMJ 1996 May 11;312(7040):1203]. BMJ. 1996;312(7036):931-934. doi:10.1136/bmj.312.7036.931 | Publication status; Publication date
363 | Chisholm, A, Mc Auley, K, Mann, J, et al. Cholesterol lowering effects of nuts compared with a Canola oil enriched cereal of similar fat composition. Nutr Metab Cardiovasc Dis. 2005. 15:284-92. doi:10.1016/j.numecd.2005.01.006 | Intervention/Exposure; Comparator
364 | Chiu S, Williams PT, Dawson T, et al. Diets high in protein or saturated fat do not affect insulin sensitivity or plasma concentrations of lipids and lipoproteins in overweight and obese adults. J Nutr. 2014;144(11):1753-1759. doi:10.3945/jn.114.197624 | Intervention/Exposure
365 | Chiu, S, Bergeron, N, Williams, PT, et al. Comparison of the DASH (Dietary Approaches to Stop Hypertension) diet and a higher-fat DASH diet on blood pressure and lipids and lipoproteins: a randomized controlled trial. Am J Clin Nutr. 2016. 103:341-7. doi:10.3945/ajcn.115.123281 | Intervention/Exposure; Duration
366 | Chiu, S, Siri-Tarino, P, Bergeron, N, et al. A Randomized Study of the Effect of Replacing Sugar-Sweetened Soda by Reduced Fat Milk on Cardiometabolic Health in Male Adolescent Soda Drinkers. Nutrients. 2020. 12:405. doi:10.3390/nu12020405 | Duration
367 | Chiu, S, Williams, PT, Krauss, RM. Effects of a very high saturated fat diet on LDL particles in adults with atherogenic dyslipidemia: A randomized controlled trial. PLoS One. 2017. 12:e0170664. doi:10.1371/journal.pone.0170664 | Intervention/Exposure; Duration
368 | Chiuve, SE, Rimm, EB, Sandhu, RK, et al. Dietary fat quality and risk of sudden cardiac death in women. Am J Clin Nutr. Sep 2012;96(3):498-507. doi:10.3945/ajcn.112.040287 | Intervention/Exposure
369 | Chiuve, SE, Sandhu, RK, Moorthy, MV, et al. Dietary Fat Intake Is Differentially Associated with Risk of Paroxysmal Compared with Sustained Atrial Fibrillation in Women. Journal of Nutrition. Sep 2015;145(9):2092-2101. doi:10.3945/jn.115.212860 | Intervention/Exposure; Outcome
370 | Chlebowski, RT, Aragaki, AK, Anderson, GL, et al. Association of Low-Fat Dietary Pattern With Breast Cancer Overall Survival: a Secondary Analysis of the Women’s Health Initiative Randomized Clinical Trial. JAMA oncology. 2018. 4:e181212. doi:10.1001/jamaoncol.2018.1212 | Intervention/Exposure; Outcome
371 | Choi, E, Ahn, S, Joung, H. Association of Dietary Fatty Acid Consumption Patterns with Risk of Hyper-LDL Cholesterolemiain Korean Adults. Nutrients. May 14 2020;12(5)doi:10.3390/nu12051412 | Intervention/Exposure
372 | Choi, SH, Gharahmany, G, Walzem, RL, et al. Ground Beef High in Total Fat and Saturated Fatty Acids Decreases X Receptor Signaling Targets in Peripheral Blood Mononuclear Cells of Men and Women. Lipids. Mar 2018;53(3):279-290. doi:10.1002/lipd.12028 | Sample size/Power
373 | Choi, WJ, Shin, D. Interactions between red and processed meat consumption and APOA5 gene variants associated with the incidence of metabolic syndrome in Korean adults. Genes Nutr. 2022. 17:5. doi:10.1186/s12263-022-00707-w | Intervention/Exposure; Outcome
374 | Choi, Y, Gallaher, DD, Svendsen, K, et al. Simple Nutrient-Based Rules vs. a Nutritionally Rich Plant-Centered Diet in Prediction of Future Coronary Heart Disease and Stroke: Prospective Observational Study in the US. Nutrients. 2022. 14:469. doi:10.3390/nu14030469 | Intervention/Exposure
375 | Choi, Y, Larson, N, Steffen, LM, et al. Plant-Centered Diet and Risk of Incident Cardiovascular Disease During Young to Middle Adulthood. J Am Heart Assoc. 2021. 10:e020718. doi:10.1161/jaha.120.020718 | Intervention/Exposure
376 | Chong YH, Ng, TKW. Effects of palm oil on cardiovascular risk. Med J Malaysia. Mar 1991;46(1):41-50. | Study design
377 | Choo, JM, Murphy, KJ, Wade, AT, et al. Interactions between Mediterranean Diet Supplemented with Dairy Foods and the Gut Microbiota Influence Cardiovascular Health in an Australian Population. Nutrients. Aug 19 2023;15(16)doi:10.3390/nu15163645 | Comparator; Sample size/Power
378 | Choudhary A, Devi RG, Jyothipriya A. Study on vegetarian or Non-vegetarian more prone to hypertension. Drug Intervention Today. 2019. | Study design; Country
379 | Choudhury, N, Truswell, AS, McNeil, Y. Comparison of plasma lipids and vitamin E in young and middle-aged subjects on potato crisps fried in palmolein and highly oleic sunflower oil. Ann Nutr Metab. 1997;41(3):137-48. doi:10.1159/000177989 | Duration
380 | Chouinard-Watkins, R, Calleja, M, Bazinet, RP, et al. Dairy product consumption is associated with a lowering of linoleic acid within serum TAG in adolescent females with overweight or obesity: A secondary analysis. British Journal of Nutrition. 2022. 127:68-77. doi:10.1017/S0007114521001677 | Outcome; Sample size/Power
381 | Chouinard-Watkins, R, Conway, V, Minihane, AM, et al. Interaction between BMI and APOE genotype is associated with changes in the plasma long-chain-PUFA response to a fish-oil supplement in healthy participants. American Journal of Clinical Nutrition. Aug 2015;102(2):505-513. doi:10.3945/ajcn.114.103507 | Intervention/Exposure
382 | Christen, T, Nagale, S, Reinitz, S, et al. Using digital health technology to evaluate the impact of chocolate on blood pressure: Results from the COCOA-BP study. Cardiovasc Digit Health J. 2020. 1:89-96. doi:10.1016/j.cvdhj.2020.08.002 | Study design; Duration
383 | Christiansen, E, Schnider, S, Palmvig, B, et al. Intake of a diet high in trans monounsaturated fatty acids or saturated fatty acids. Effects on postprandial insulinemia and glycemia in obese patients with NIDDM. Diabetes Care. 1997. 20:881-7. doi:10.2337/diacare.20.5.881 | Intervention/Exposure; Sample size/Power
384 | Christiansen, LI, Lähteenmäki, PL, Mannelin, MR, et al. Cholesterol-lowering effect of spreads enriched with microcrystalline plant sterols in hypercholesterolemic subjects. Eur J Nutr. Apr 2001;40(2):66-73. doi:10.1007/s003940170017 | Intervention/Exposure; Comparator
385 | Christofaro, DG, Fernandes, RA, Oliveira, AR, et al. The Association Between Cardiovascular Risk Factors and High Blood Pressure in Adolescents: A School-Based Study. American Journal of Human Biology. Jul-Aug 2014;26(4):518-522. doi:10.1002/ajhb.22555 | Study design
386 | Christophe, AB, De Greyt, WF, Delanghe, JR, et al. Substituting enzymatically interesterified butter for native butter has no effect on lipemia or lipoproteinemia in Man. Ann Nutr Metab. 2000. 44:61-7. doi:10.1159/000012822 | Comparator; Sample size/Power
387 | Chu FL, Kies C, Clemens ET. Studies of human diets with pork, beef, fish, soybean, and poultry: Nitrogen and fat utilization, and blood serum chemistry. Journal of Applied Nutrition. 1995;47(3): 51-66. | Sample size/Power
388 | Chu TM, Cheng HH, Lin YJ, et al. Lowering dietary fat changes plasma lipids and the fatty acid composition in young adults. Nutritional Sciences Journal. 2006;31(3):77-86. | Study design; Country
389 | Chuang, SY, Chang, HY, Fang, HL, et al. The Healthy Taiwanese Eating Approach is inversely associated with all-cause and cause-specific mortality: A prospective study on the Nutrition and Health Survey in Taiwan, 1993-1996. PLoS One. 2021. 16:e0251189. doi:10.1371/journal.pone.0251189 | Intervention/Exposure; Outcome
390 | Chung, S, Chung, MY, Choi, HK, et al. Animal Protein Intake Is Positively Associated with Metabolic Syndrome Risk Factors in Middle-Aged Korean Men. Nutrients. Nov 2020;12(11)doi:ARTN 341510.3390/nu12113415 | Study design
391 | Ciccarone, E, Di Castelnuovo, A, Salcuni, M, et al. A high-score Mediterranean dietary pattern is associated with a reduced risk of peripheral arterial disease in Italian patients with Type 2 diabetes. J Thromb Haemost. 2003. 1:1744-52. doi:10.1046/j.1538-7836.2003.00323.x | Health status
392 | Cicero AFG, Fogacci F, Grandi E, et al. Prevalent Seasoning and Cooking Fats, Arterial Stiffness and Blood Lipid Pattern in a Rural Population Sample: Data from the Brisighella Heart Study. Nutrients. 2020;12(10):3063. Published 2020 Oct 7. doi:10.3390/nu12103063 | Study design; Intervention/Exposure
393 | Ciobanu, A. Eating chocolate twice a week reduces heart failure incidence. Maedica (Bucur). Jul 2010;5(3):219. | Study design
394 | Claessens, M, Van Baak, MA, Monsheimer, S, et al. The effect of a low-fat, high-protein or high-carbohydrate ad libitum diet on weight loss maintenance and metabolic risk factors. International Journal of Obesity. 2009. 33:296-304. doi:10.1038/ijo.2008.278 | Intervention/Exposure
395 | Clarke, R, Shipley, M, Armitage, J, et al. Plasma phospholipid fatty acids and CHD in older men: Whitehall study of London civil servants. Br J Nutr. 2009. 102:279-84. doi:10.1017/s0007114508143562 | Intervention/Exposure
396 | Cleghorn, CL, Skeaff, CM, Mann, J, et al. Plant sterol-enriched spread enhances the cholesterol-lowering potential of a fat-reduced diet. Eur J Clin Nutr. 2003. 57:170-6. doi:10.1038/sj.ejcn.1601531 | Intervention/Exposure; Duration; Comparator
397 | Clemente, G, Giorgini, M, Della Pia, N, et al. Effectiveness on major cardiovascular risk factors of an educational program to promote a Mediterranean type of diet among the employees of the company FCA Italia S.p.A. Diabetes Res Clin Pract. 2021. 179:109009. doi:10.1016/j.diabres.2021.109009 | Intervention/Exposure
398 | Clevidence, BA, Judd, JT, Schaefer, EJ, et al. Plasma lipoprotein (a) levels in men and women consuming diets enriched in saturated, cis-, or trans-monounsaturated fatty acids. Arterioscler Thromb Vasc Biol. Sep 1997;17(9):1657-61. doi:10.1161/01.atv.17.9.1657 | Intervention/Exposure
399 | Clevidence, BA, Judd, JT, Schatzkin, A, et al. Plasma lipid and lipoprotein concentrations of men consuming a low-fat, high-fiber diet. Am J Clin Nutr. Mar 1992;55(3):689-94. doi:10.1093/ajcn/55.3.689 | Intervention/Exposure
400 | Clifton PM, Noakes M, Keogh J, Foster P. Effect of an energy reduced high protein red meat diet on weight loss and metabolic parameters in obese women. Asia Pacific Journal of Clin Nutr. 2003. 12 Suppl: S10. | Study design; Publication status
401 | Clifton, PM, Kestin, M, Abbey, M, et al. Relationship between Sensitivity to Dietary-Fat and Dietary-Cholesterol. Arteriosclerosis. May-Jun 1990;10(3):394-401. doi:Doi 10.1161/01.Atv.10.3.394 | Intervention/Exposure; Comparator
402 | Clifton, PM, Noakes, M, Keogh, JB. Very low-fat (12%) and high monounsaturated fat (35%) diets do not differentially affect abdominal fat loss in overweight, nondiabetic women. J Nutr. 2004. 134:1741-5. doi:10.1093/jn/134.7.1741 | Intervention/Exposure
403 | Clifton, PM, Noakes, M, Sullivan, D, et al. Cholesterol-lowering effects of plant sterol esters differ in milk, yoghurt, bread and cereal. Eur J Clin Nutr. 2004. 58:503-9. doi:10.1038/sj.ejcn.1601837 | Duration; Comparator
404 | Clifton, PM. Protein and coronary heart disease: The role of different protein sources. Current Atherosclerosis Reports. 2011. 13:493-498. doi:10.1007/s11883-011-0208-x | Study design
405 | Coates, AM, Sioutis, S, Buckley, JD, et al. Regular consumption of n-3 fatty acidenriched pork modifies cardiovascular risk factors. Br J Nutr. 2009. 101:592-7. doi:10.1017/s0007114508025063 | Comparator; Sample size/Power
406 | Cobb, MM, Risch, N. Low-density lipoprotein cholesterol responsiveness to diet in normolipidemic subjects. Metabolism. Jan 1993;42(1):7-13. doi:10.1016/0026-0495(93)90164-j | Intervention/Exposure
407 | Cobb, MM, Teitlebaum, H, Risch, N, et al. Influence of dietary fat, apolipoprotein E phenotype, and sex on plasma lipoprotein levels. Circulation. Sep 1992;86(3):849-57. doi:10.1161/01.cir.86.3.849 | Intervention/Exposure
408 | Cobb, MM, Teitlebaum, H. Determinants of plasma cholesterol responsiveness to diet. Br J Nutr. Feb 1994;71(2):271-82. doi:10.1079/bjn19940133 | Intervention/Exposure
409 | CocoaVia: chocolate that helps the heart? Consumer Reports. 2006;71(7):51-51. | Study design
410 | Coelho, SB, de Sales, RL, Iyer, SS, et al. Effects of peanut oil load on energy expenditure, body composition, lipid profile, and appetite in lean and overweight adults. Nutrition. 2006. 22:585-92. doi:10.1016/j.nut.2006.03.012 | Intervention/Exposure; Comparator
411 | Cogan, B, Pearson, RC, Jenkins, NT, et al. A 4-Week Pecan-Enriched Diet Improves Postprandial Lipid Peroxidation in Aging Adults. Article in Press. J Med Food. Sep 2023;26(9):654-662. doi:10.1089/jmf.2023.0036 | Intervention/Exposure; Sample size/Power
412 | Colombo, C, Muti, P, Pala, V, et al. Plant-based diet, serum fatty acid profile, and free radicals in postmenopausal women: the diet and androgens (DIANA) randomized trial. Int J Biol Markers. 2005. 20:169-76. doi:10.1177/172460080502000304 | Intervention/Exposure
413 | Conlin, PR, Chow, D, Miller, ER, et al. The effect of dietary patterns on blood pressure control in hypertensive patients: results from the Dietary Approaches to Stop Hypertension (DASH) trial. Am J Hypertens. 2000. 13:949-55. doi:10.1016/s0895-7061(99)00284-8 | Intervention/Exposure
414 | Conlin, PR, Erlinger, TP, Bohannon, A, et al. The DASH diet enhances the blood pressure response to losartan in hypertensive patients. Am J Hypertens. 2003. 16:337-42. doi:10.1016/s0895-7061(03)00056-6 | Intervention/Exposure; Comparator
415 | Conlin, PR. The dietary approaches to stop hypertension (DASH) clinical trial: implications for lifestyle modifications in the treatment of hypertensive patients. Cardiol Rev. Sep-Oct 1999;7(5):284-8. doi:10.1097/00045415-199909000-00013 | Intervention/Exposure
416 | Connor, SL, Gustafson, JR, Sexton, G, et al. The Diet Habit Survey - a New Method of Dietary Assessment That Relates to Plasma-Cholesterol Changes. Journal of the American Dietetic Association. Jan 1992;92(1):41-47. | Intervention/Exposure
417 | Conway V, Couture P, Richard C, Gauthier SF, Pouliot Y, Lamarche B. Impact of buttermilk consumption on plasma lipids and surrogate markers of cholesterol homeostasis in men and women. Nutr Metab Cardiovasc Dis. 2013;23(12):1255-1262. doi:10.1016/j.numecd.2013.03.003 | Intervention/Exposure
418 | Conway, V, Couture, P, Gauthier, S, et al. Effect of buttermilk consumption on blood pressure in moderately hypercholesterolemic men and women. Nutrition. 2014. 30:116-9. doi:10.1016/j.nut.2013.07.021 | Comparator
419 | Corella, D, Portolés, O, Arriola, L, et al. Saturated fat intake and alcohol consumption modulate the association between the APOE polymorphism and risk of future coronary heart disease: a nested case-control study in the Spanish EPIC cohort. J Nutr Biochem. 2011. 22:487-94. doi:10.1016/j.jnutbio.2010.04.003 | Intervention/Exposure
420 | Cormier, H, Thifault, É, Garneau, V, et al. Association between yogurt consumption, dietary patterns, and cardio-metabolic risk factors. Eur J Nutr. 2016. 55:577-587. doi:10.1007/s00394-015-0878-1 | Study design
421 | Correction: Habitual chocolate consumption and risk of cardiovascular disease among healthy men and women. Heart. 2018;104(6):532. doi:10.1136/heartjnl-2014-307050corr1 | Study design; Publication status
422 | Corrigendum: Effects of red meat, white meat, and nonmeat protein sources on atherogenic lipoprotein measures in the context of low compared with high saturated fat intake: a randomized controlled trial. Am J Clin Nutr 2019;110:24-33. Am J Clin Nutr. 2019;110(3):783. doi:10.1093/ajcn/nqz143 | Study design
423 | Costa, ESilvaLM, Pereira de Melo, ML, Faro Reis, FV, et al. Comparison of the Effects of Brazil Nut Oil and Soybean Oil on the Cardiometabolic Parameters of Patients with Metabolic Syndrome: A Randomized Trial. Nutrients. Dec 23 2019;12(1)doi:10.3390/nu12010046 | Intervention/Exposure; Sample size/Power
424 | Couch, SC, Saelens, BE, Levin, L, et al. The efficacy of a clinic-based behavioral nutrition intervention emphasizing a DASH-type diet for adolescents with elevated blood pressure. J Pediatr. 2008. 152:494-501. doi:10.1016/j.jpeds.2007.09.022 | Intervention/Exposure
425 | Cowin, IS, Emmett, PM. Associations between dietary intakes and blood cholesterol concentrations at 31 months. European Journal of Clinical Nutrition. Jan 2001;55(1):39-49. doi:DOI 10.1038/sj.ejcn.1601120 | Population
426 | Cox, C, Mann, J, Sutherland, W, et al. Effects of coconut oil, butter, and safflower oil on lipids and lipoproteins in persons with moderately elevated cholesterol levels. J Lipid Res. Aug 1995;36(8):1787-95. | Sample size/Power
427 | Cox, C, Mann, J, Sutherland, W, et al. Individual variation in plasma cholesterol response to dietary saturated fat. BMJ. Nov 11 1995;311(7015):1260-4. doi:10.1136/bmj.311.7015.1260 | Intervention/Exposure
428 | Cox, CM, Sutherland, WH, Ball, MJ, et al. Response of plasma lathosterol concentration to change in the quality of dietary fat in men and women. Eur J Clin Nutr. Jun 1996;50(6):358-63. | Intervention/Exposure
429 | Crews Jr, WD, Harrison, DW, Wright, JW. A double-blind, placebo-controlled, randomized trial of the effects of dark chocolate and cocoa on variables associated with neuropsychological functioning and cardiovascular health: Clinical findings from a sample of healthy, cognitively intact older adults. American Journal of Clinical Nutrition. 2008. 87:872-880. doi:10.1093/ajcn/87.4.872 | Intervention/Exposure; Comparator
430 | Crichton GE, Howe PR, Buckley JD, Coates AM, Murphy KJ. Dairy consumption and cardiometabolic health: outcomes of a 12-month crossover trial. Nutr Metab (Lond). 2012;9:19. Published 2012 Mar 20. doi:10.1186/1743-7075-9-19 | Sample size/Power
431 | Crichton, GE, Alkerwi, A. Dairy food intake is positively associated with cardiovascular health: findings from Observation of Cardiovascular Risk Factors in Luxembourg study. Nutr Res. 2014. 34:1036-44. doi:10.1016/j.nutres.2014.04.002 | Study design
432 | Crichton, GE, Elias, MF, Alkerwi, A, et al. Relation of Habitual Chocolate Consumption to Arterial Stiffness in a Community-Based Sample: Preliminary Findings. Pulse (Basel). Jul 2016;4(1):28-37. doi:10.1159/000445876 | Outcome
433 | Crimarco, A, Springfield, S, Petlura, C, et al. A randomized crossover trial on the effect of plant-based compared with animal-based meat on trimethylamine-N-oxide and cardiovascular disease risk factors in generally healthy adults: study With Appetizing Plantfood-Meat Eating Alternative Trial (SWAP-MEAT). American journal of clinical nutrition. 2020. 112:1188-1199. doi:10.1093/ajcn/nqaa203 | Intervention/Exposure
434 | Crippa G, Bosi M, Cassi A, et al. Antihypertensive effect of dietary integration with grana padano cheese in hypertensive patients. Journal of Hypertension. 2011;29:e27. | Study design; Publication status
435 | Crippa, G, Zabzuni, D, Bravi, E, et al. Antihypertensive Effect of Milk-Derivative Tripeptides. Randomized, Double-Blind, Placebo-Controlled Study on the Effects of Grana Padano Cheese Dop in Hypertensive Patients. Journal of Hypertension. Sep 2016;34:E55-E56. doi:DOI 10.1097/01.hjh.0000499995.03316.c3 | Publication status
436 | Crouse, SF, Green, JS, Meade, TH, et al. Exercise raises high-density lipoprotein cholesterol in men after consumption of ground beef with a high but not low monounsaturated fatty acid-saturated fatty acid ratio. Nutr Res. 2016. 36:974-981. doi:10.1016/j.nutres.2016.06.013 | Sample size/Power
437 | Cuchel, M, Schwab, US, Jones, PJ, et al. Impact of hydrogenated fat consumption on endogenous cholesterol synthesis and susceptibility of low-density lipoprotein to oxidation in moderately hypercholesterolemic individuals. Metabolism. 1996. 45:241-7. doi:10.1016/s0026-0495(96)90061-x | Sample size/Power
438 | Curb, JD, Wergowske, G, Dobbs, JC, et al. Serum lipid effects of a highmonounsaturated fat diet based on macadamia nuts. Arch Intern Med. 2000. 160:1154-8. doi:10.1001/archinte.160.8.1154 | Intervention/Exposure; Comparator
439 | Currenti, W, Godos, J, Alanazi, AM, et al. Dietary Fats and Cardio-Metabolic Outcomes in a Cohort of Italian Adults. Nutrients. Oct 14 2022;14(20)doi:10.3390/nu14204294 | Intervention/Exposure
440 | Czekajło, A, Różańska, D, Zatońska, K, et al. Association between dietary patterns and cardiovascular risk factors in a selected population of Lower Silesia (PURE Study Poland). Ann Agric Environ Med. 2018. 25:635-641. doi:10.26444/aaem/76321 | Intervention/Exposure
441 | Da Silva, MS, Julien, P, Couture, P, et al. Associations between dairy intake and metabolic risk parameters in a healthy French-Canadian population. Appl Physiol Nutr Metab. 2014. 39:1323-31. doi:10.1139/apnm-2014-0154 | Study design
442 | Dabadie H, Motta C, Peuchant E, LeRuyet P, Mendy F. Variations in daily intakes of myristic and alpha-linolenic acids in sn-2 position modify lipid profile and red blood cell membrane fluidity. Br J Nutr. 2006;96(2):283-289. doi:10.1079/bjn20061813 | Intervention/Exposure; Outcome
443 | Dabadie, H, Peuchant, E, Bernard, M, et al. Moderate intake of myristic acid in sn-2 position has beneficial lipidic effects and enhances DHA of cholesteryl esters in an interventional study. J Nutr Biochem. 2005. 16:375-82. doi:10.1016/j.jnutbio.2005.01.010 | Intervention/Exposure; Sample size/Power
444 | Dainelli, L, Xu, T, Li, M, et al. Cost-effectiveness of milk powder fortified with potassium to decrease blood pressure and prevent cardiovascular events among the adult population in China: a Markov model. BMJ Open. 2017. 7:e017136. doi:10.1136/bmjopen-2017-017136 | Study design; Intervention/Exposure
445 | Dale, KS, McAuley, KA, Taylor, RW, et al. Determining optimal approaches for weight maintenance: a randomized controlled trial. CMAJ. May 12 2009;180(10):E39-46. doi:10.1503/cmaj.080974 | Intervention/Exposure
446 | Dalla Zuanna, T, Batzella, E, Russo, F, et al. Migrant status disparities in blood pressure: a multiple mediation analysis of modifiable factors. J Epidemiol Glob Health. Sep 2023;13(3):547-556. doi:10.1007/s44197-023-00136-x | Study design
447 | Dalle Grave, R, Calugi, S, Gavasso, I, et al. A randomized trial of energy-restricted high-protein versus high-carbohydrate, low-fat diet in morbid obesity. Obesity (Silver Spring). Sep 2013;21(9):1774-81. doi:10.1002/oby.20320 | Intervention/Exposure
448 | Dallongeville, J, Leboeuf, N, Blais, C, et al. Short-term response to dietary counseling of hyperlipidemic outpatients of a lipid clinic. J Am Diet Assoc. Jun 1994;94(6):616-21. doi:10.1016/0002-8223(94)90156-2 | Intervention/Exposure
449 | Daly, RM, Gianoudis, J, de Ross, B, et al. Effects of a multinutrient-fortified milk drink combined with exercise on functional performance, muscle strength, body composition, inflammation, and oxidative stress in middle-aged women: a 4-month, double-blind, placebo-controlled, randomized trial. Am J Clin Nutr. Aug 1 2020;112(2):427-446. doi:10.1093/ajcn/nqaa126 | Intervention/Exposure; Comparator
450 | Daly, RM, Nowson, CA. Long-term effect of calcium-vitamin D(3) fortified milk on blood pressure and serum lipid concentrations in healthy older men. Eur J Clin Nutr. 2009. 63:993-1000. doi:10.1038/ejcn.2008.79 | Comparator
451 | Damião R, Sartorelli DS, Hirai A, et al. Impacto de um programa de intervenção sobre o estilo de vida nos perfis metabólico, antropométrico e dietético em nipo-brasileiros com e sem síndrome metabólica [Impact of a lifestyle intervention program on metabolic, anthropometrical and dietary profile of Japanese-Brazilians with and without metabolic syndrome]. Arq Bras Endocrinol Metabol. 2011;55(2):134-145. doi:10.1590/S0004-27302011000200006. | Study design; Publication language
452 | Damião, R, Castro, TG, Cardoso, MA, et al. Dietary intakes associated with metabolic syndrome in a cohort of Japanese ancestry. Br J Nutr. Sep 2006;96(3):532-8. | Outcome
453 | Damigou E, Kosti RI, Anastasiou C, et al. Associations between meat type consumption pattern and incident cardiovascular disease: The ATTICA epidemiological cohort study (2002-2022). Meat Sci. 2023;205:109294. doi:10.1016/j.meatsci.2023.109294 | Comparator
454 | Damsgaard, CT, Ritz, C, Dalskov, SM, et al. Associations between school meal-induced dietary changes and metabolic syndrome markers in 8–11-year-old Danish children. European Journal of Nutrition. 2016. 55:1973-1984. doi:10.1007/s00394-0151013-z | Intervention/Exposure
455 | Dashti, HM, Mathew, TC, Hussein, T, et al. Long-term effects of a ketogenic diet in obese patients. Exp Clin Cardiol. Fall 2004;9(3):200-5. | Study design; Intervention/Exposure; Comparator
456 | Dauchet, L, Kesse-Guyot, E, Czernichow, S, et al. Dietary patterns and blood pressure change over 5-y follow-up in the SU.VI.MAX cohort. Am J Clin Nutr. 2007. 85:1650-6. doi:10.1093/ajcn/85.6.1650 | Comparator
457 | Davidson, MH, Hunninghake, D, Maki, KC, et al. Comparison of the effects of lean red meat vs lean white meat on serum lipid levels among free-living persons with hypercholesterolemia: A long- term, randomized clinical trial. Archives of Internal Medicine. 1999. 159:1331-1338. doi:10.1001/archinte.159.12.1331 | Comparator
458 | Davidson, MH, Kong, JC, Drennan, KB, et al. Efficacy of the National Cholesterol Education Program Step I diet. A randomized trial incorporating quick-service foods. Arch Intern Med. Feb 12 1996;156(3):305-12. | Intervention/Exposure
459 | Davis, CR, Bryan, J, Hodgson, JM, et al. A Mediterranean Diet Reduces F(2)-Isoprostanes and Triglycerides among Older Australian Men and Women after 6 Months. J Nutr. 2017. 147:1348-1355. doi:10.3945/jn.117.248419 | Intervention/Exposure
460 | Davis, CR, Hodgson, JM, Woodman, R, et al. A Mediterranean diet lowers blood pressure and improves endothelial function: results from the MedLey randomized intervention trial. Am J Clin Nutr. 2017. 105:1305-1313. doi:10.3945/ajcn.116.146803 | Intervention/Exposure
461 | Davis, KE, Prasad, C, Imrhan, V. Consumption of a diet rich in cottonseed oil (CSO) lowers total and LDL cholesterol in normo-cholesterolemic subjects. Nutrients. 2012. 4:602-10. doi:10.3390/nu4070602 | Study design; Intervention/Exposure; Duration
462 | Davis, KM, Petersen, KS, Bowen, KJ, et al. Effects of Diets Enriched with Conventional or High-Oleic Canola Oils on Vascular Endothelial Function: A Sub-Study of the Canola Oil Multi-Centre Intervention Trial 2 (COMIT-2), a Randomized Crossover Controlled Feeding Study. Nutrients. Aug 18 2022;14(16)doi:10.3390/nu14163404 | Outcome
463 | Davis, PA, Platon, JF, Gershwin, ME, et al. A linoleate-enriched cheese product reduces low-density lipoprotein in moderately hypercholesterolemic adults. Ann Intern Med. Oct 1 1993;119(7 Pt 1):555-9. doi:10.7326/0003-4819-119-7_part_1-199310010-00002 | Sample size/Power
464 | Dawczynski, C, Martin, L, Wagner, A, et al. n-3 LC-PUFA-enriched dairy products are able to reduce cardiovascular risk factors: a double-blind, cross-over study. Clin Nutr. 2010. 29:592-9. doi:10.1016/j.clnu.2010.02.008 | Comparator
465 | de Goede J, Verschuren WM, Boer JM, Kromhout D, Geleijnse JM. Alpha-linolenic acid intake and 10-year incidence of coronary heart disease and stroke in 20,000 middleaged men and women in the Netherlands. PLoS One. 2011;6(3):e17967. Published 2011 Mar 25. doi:10.1371/journal.pone.0017967 | Intervention/Exposure
466 | De Graaf J, De Sauvage Nolting PR, Van Dam M, et al. Consumption of tall oil-derived phytosterols in a chocolate matrix significantly decreases plasma total and low-density lipoprotein-cholesterol levels. Br J Nutr. 2002;88(5):479-488. doi:10.1079/BJN2002690 | Intervention/Exposure; Comparator
467 | de Jong, A, Plat, J, Lütjohann, D, et al. Effects of long-term plant sterol or stanol ester consumption on lipid and lipoprotein metabolism in subjects on statin treatment. Br J Nutr. 2008. 100:937-41. doi:10.1017/s0007114508966113 | Intervention/Exposure; Comparator
468 | de Jong, N, Zuur, A, Wolfs, MC, et al. Exposure and effectiveness of phytosterol/-stanol-enriched margarines. Eur J Clin Nutr. 2007. 61:1407-15. doi:10.1038/sj.ejcn.1602660 | Intervention/Exposure; Comparator
469 | de la O V, Zazpe I, Goni L, et al. A score appraising Paleolithic diet and the risk of cardiovascular disease in a Mediterranean prospective cohort. Eur J Nutr. 2022;61(2):957-971. doi:10.1007/s00394-021-02696-9 | Intervention/Exposure
470 | de Leeuw PW, van der Zander K, Kroon AA, Rennenberg RM, Koning MM. Dose-dependent lowering of blood pressure by dairy peptides in mildly hypertensive subjects. Blood Press. 2009;18(1-2):44-50. doi:10.1080/08037050902761209 | Intervention/Exposure; Comparator
471 | de Luis DA, Izaola O, Primo D, Aller R. Different effects of high-protein/lowcarbohydrate versus standard hypocaloric diet on insulin resistance and lipid profile: Role of rs16147 variant of neuropeptide Y. Diabetes Res Clin Pract. 2019;156:107825. doi:10.1016/j.diabres.2019.107825 | Intervention/Exposure
472 | de Luis DA, Romero E, Izaola O, Primo D, Aller R. Cardiovascular Risk Factors and Insulin Resistance after Two Hypocaloric Diets with Different Fat Distribution in Obese Subjects: Effect of the rs10767664 Gene Variant in Brain-Derived Neurotrophic Factor. J Nutrigenet Nutrigenomics. 2017;10(5-6):163-171. doi:10.1159/000485248 | Intervention/Exposure
473 | De Luis, DA, Izaola, O, Aller, R, et al. Effects of a high-protein/low carbohydrate versus a standard hypocaloric diet on adipocytokine levels and insulin resistance in obese patients along 9 months. J Diabetes Complications. Sep-Oct 2015;29(7):950-4. doi:10.1016/j.jdiacomp.2015.06.002 | Intervention/Exposure
474 | De Oliveira Mota, J, Boué, G, Guillou, S, et al. Estimation of the burden of disease attributable to red meat consumption in France: Influence on colorectal cancer and cardiovascular diseases. Food Chem Toxicol. Aug 2019;130:174-186. doi:10.1016/j.fct.2019.05.023 | Study design; Intervention/Exposure
475 | de Oliveira Otto MC, Afshin A, Micha R, et al. The Impact of dietary and metabolic risk factors on cardiovascular diseases and type 2 diabetes mortality in Brazil. PLoS One. 2016;11(3):e0151503. doi:10.1371/journal.pone.0151503 | Study design
476 | de Oliveira Otto MC, Mozaffarian D, Kromhout D, et al. Dietary intake of saturated fat by food source and incident cardiovascular disease: the Multi-Ethnic Study of Atherosclerosis. Am J Clin Nutr. 2012;96(2):397-404. doi:10.3945/ajcn.112.037770 | Intervention/Exposure; Comparator
477 | de Oliveira Otto, MC, Alonso, A, Lee, DH, et al. Dietary intakes of zinc and heme iron from red meat, but not from other sources, are associated with greater risk of metabolic syndrome and cardiovascular disease. J Nutr. Mar 2012;142(3):526-33. doi:10.3945/jn.111.149781 | Intervention/Exposure
478 | de Oliveira Otto, MC, Lemaitre, RN, Song, X, et al. Serial measures of circulating biomarkers of dairy fat and total and cause-specific mortality in older adults: the Cardiovascular Health Study. Am J Clin Nutr. 2018. 108:476-484. doi:10.1093/ajcn/nqy117 | Intervention/Exposure
479 | de Oliveira Otto, MC, Nettleton, JA, Lemaitre, RN, et al. Biomarkers of dairy fatty acids and risk of cardiovascular disease in the Multi-ethnic Study of Atherosclerosis. J Am Heart Assoc. 2013. 2:e000092. doi:10.1161/jaha.113.000092 | Intervention/Exposure
480 | de Oliveira PA, Kovacs C, Moreira P, Magnoni D, Saleh MH, Faintuch J. Unsaturated Fatty Acids Improve Atherosclerosis Markers in Obese and Overweight Non-diabetic Elderly Patients. Obes Surg. 2017;27(10):2663-2671. doi:10.1007/s11695-017-2704-8 | Intervention/Exposure
481 | de Roos N, Schouten E, Katan M. Consumption of a solid fat rich in lauric acid results in a more favorable serum lipid profile in healthy men and women than consumption of a solid fat rich in trans-fatty acids. J Nutr. 2001;131(2):242-245. doi:10.1093/jn/131.2.242 | Intervention/Exposure; Sample size/Power
482 | de Roos NM, Bots ML, Siebelink E, Schouten E, Katan MB. Flow-mediated vasodilation is not impaired when HDL-cholesterol is lowered by substituting carbohydrates for monounsaturated fat. Br J Nutr. 2001;86(2):181-188. doi:10.1079/bjn2001365 | Intervention/Exposure; Duration
483 | de Roos NM, Schouten G, Katan MB. Yoghurt enriched with Lactobacillus acidophilus does not lower blood lipids in healthy men and women with normal to borderline high serum cholesterol levels. Eur J Clin Nutr. 1999;53(4):277-280. doi:10.1038/sj.ejcn.1600722 | Intervention/Exposure; Comparator
484 | de Roos, NM, Bots, ML, Katan, MB. Replacement of dietary saturated fat with trans fat reduces serum paraoxonase activity in healthy men and women. Metabolism. Dec 2002;51(12):1534-7. doi:10.1053/meta.2002.36305 | Comparator; Sample size/Power
485 | de Roos, NM, Schouten, EG, Katan, MB. Trans fatty acids, HDL-cholesterol, and cardiovascular disease. Effects of dietary changes on vascular reactivity. Eur J Med Res. Aug 20 2003;8(8):355-7. | Intervention/Exposure; Duration; Sample size/Power
486 | de Roos, NM, Schouten, EG, Scheek, LM, et al. Replacement of dietary saturated fat with trans fat reduces serum paraoxonase activity in healthy men and women. Metabolism. 2002. 51:1534-7. doi:10.1053/meta.2002.36305 | Intervention/Exposure
487 | de Roos, NM, Siebelink, E, Bots, ML, et al. Trans monounsaturated fatty acids and saturated fatty acids have similar effects on postprandial flow-mediated vasodilation. Eur J Clin Nutr. 2002. 56:674-9. doi:10.1038/sj.ejcn.1601377 | Duration; Sample size/Power
488 | de Souza RGM, Gomes AC, de Castro IA, Mota JF. A baru almond-enriched diet reduces abdominal adiposity and improves high-density lipoprotein concentrations: a randomized, placebo-controlled trial. Nutrition. 2018;55-56:154-160. doi:10.1016/j.nut.2018.06.001 | Intervention/Exposure
489 | de Souza RJ, Dehghan M, Mente A, et al. Association of nut intake with risk factors, cardiovascular disease, and mortality in 16 countries from 5 continents: analysis from the Prospective Urban and Rural Epidemiology (PURE) study. Am J Clin Nutr. 2020;112(1):208-219. doi:10.1093/ajcn/nqaa108 | Intervention/Exposure
490 | Dehghan, M, Mente, A, Rangarajan, S, et al. Association of dairy intake with cardiovascular disease and mortality in 21 countries from five continents (PURE): a prospective cohort study. Lancet. 2018. 392:2288-2297. doi:10.1016/s01406736(18)31812-9 | Comparator
491 | Dehghan, M, Mente, A, Zhang, X, et al. Associations of fats and carbohydrate intake with cardiovascular disease and mortality in 18 countries from five continents (PURE): a prospective cohort study. Lancet. 2017. 390:2050-2062. doi:10.1016/s01406736(17)32252-3 | Intervention/Exposure
492 | Del Bó, C, Simonetti, P, Gardana, C, et al. Horse meat consumption affects iron status, lipid profile and fatty acid composition of red blood cells in healthy volunteers. Int J Food Sci Nutr. Mar 2013;64(2):147-54. doi:10.3109/09637486.2012.728198 | Intervention/Exposure; Comparator
493 | dela Paz C, Jimeno C, Sy R, et al. The effect of virgin coconut oil on lipid profile and fasting blood sugar: A phase I clinical trial. Philippine Journal of Internal Medicine. 2010;48(2). doi. org/10.3860/PJIM.V48I2.2632 | Country; Sample size/Power
494 | Delavar, MA, Lye, MS, Khor, GL, et al. Dietary patterns and the metabolic syndrome in middle aged women, Babol, Iran. Asia Pac J Clin Nutr. 2009;18(2):285-92. | Study design; Intervention/Exposure
495 | Delgado, M, González-Gross, M, Cano, MD, et al. Physical exercise reverses dietinduced increases in LDL-cholesterol and apo B levels in healthy ovo-lactovegetarian subjects. Nutrition Research. Dec 2000;20(12):1707-1714. doi:Doi 10.1016/S0271-5317(00)00276-1 | Sample size/Power
496 | Delgado, M, Gutiérrez, A, Cano, MD, et al. Elimination of meat, fish, and derived products from the Spanish-Mediterranean diet: effect on the plasma lipid profile. Ann Nutr Metab. 1996. 40:202-11. doi:10.1159/000177915 | Study design; Sample size/Power
497 | Delgado-Alarcon JM, Hernandez Morante JJ, Morillas-Ruiz JM. Modification of Breakfast Fat Composition Can Modulate Cytokine and Other Inflammatory Mediators in Women: A Randomized Crossover Trial. Article. Nutrients. Aug 24 2023;15(17)doi:10.3390/nu15173711 | Intervention/Exposure; Sample size/Power
498 | Delgado-Pando, G, Celada, P, Sánchez-Muniz, FJ, et al. Effects of improved fat content of frankfurters and pâtés on lipid and lipoprotein profile of volunteers at increased cardiovascular risk: a placebo-controlled study. Eur J Nutr. 2014. 53:83-93. doi:10.1007/s00394-013-0502-1 | Duplicate; Sample size/Power
499 | den Boer AT, Herraets IJ, Stegen J, et al. Prevention of the metabolic syndrome in IGT subjects in a lifestyle intervention: results from the SLIM study. Nutr Metab Cardiovasc Dis. Nov 2013;23(11):1147-53. doi:10.1016/j.numecd.2012.12.005 | Intervention/Exposure
500 | Dengel JL, Katzel LI, Goldberg AP. Effect of an American Heart Association diet, with or without weight loss, on lipids in obese middle-aged and older men. Am J Clin Nutr. 1995;62(4):715-721. doi:10.1093/ajcn/62.4.715 | Intervention/Exposure; Sample size/Power
501 | Denke, MA, Frantz, ID, Jr. Response to a cholesterol-lowering diet: efficacy is greater in hypercholesterolemic subjects even after adjustment for regression to the mean. Am J Med. 1993. 94:626-31. doi:10.1016/0002-9343(93)90215-b | Intervention/Exposure; Comparator
502 | Denke, MA, Grundy, SM. Individual responses to a cholesterol-lowering diet in 50 men with moderate hypercholesterolemia. Arch Intern Med. Feb 14 1994;154(3):317-25. | Intervention/Exposure
503 | Denke, MA. Individual responsiveness to a cholesterol-lowering diet in postmenopausal women with moderate hypercholesterolemia. Arch Intern Med. Sep 12 1994;154(17):1977-82. | Intervention/Exposure
504 | Dennis, BH, Stewart, P, Wang, CH, et al. Diet design for a multicenter controlled feeding trial: the DELTA program. Delta Research Group. J Am Diet Assoc. Jul 1998;98(7):766-76. doi:10.1016/s0002-8223(98)00173-4 | Study design; Intervention/Exposure
505 | Denova-Gutiérrez, E, Tucker, KL, Flores, M, et al. Dietary Patterns Are Associated with Predicted Cardiovascular Disease Risk in an Urban Mexican Adult Population. J Nutr. 2016. 146:90-7. doi:10.3945/jn.115.217539 | Intervention/Exposure
506 | Derosa, G, D’Angelo, A, Romano, D, et al. Response to an oral fat load and effects on lipid profile, glycemia and high-sensitivity C-reactive protein after soybean extract consumption. Arch Med Sci. 2018. 14:760-765. doi:10.5114/aoms.2017.70993 | Intervention/Exposure; Duration
507 | Desch, S, Kobler, D, Schmidt, J, et al. Low vs. higher-dose dark chocolate and blood pressure in cardiovascular high-risk patients. Am J Hypertens. 2010. 23:694-700. doi:10.1038/ajh.2010.29 | Health status
508 | Deshpande, AV, Anand, L, Ravikumar, BP. A study on risk factors for overweight and obesity among urban women aged 30 to 40 yrs. Article. Journal of Cardiovascular Disease Research. 2023;14(4):339-345. doi:10.31838/jcdr.2023.14.04.42 | Study design; Country
509 | Deshpande, N, Mamata, AH, Parmaj, R, et al. The immediate impact of a balanced, very low-calorie diet on the metabolic health of Indian subjects - A prospective longitudinal study. Article. Clinical Epidemiology and Global Health. Nov-Dec 2023;24doi:ARTN 10139710.1016/j.cegh.2023.101397 | Intervention/Exposure; Country
510 | Desroches, S, Archer, WR, Paradis, ME, et al. Baseline plasma C-reactive protein concentrations influence lipid and lipoprotein responses to low-fat and high monounsaturated fatty acid diets in healthy men. Journal of Nutrition. 2006. 136:1005-1011. doi:10.1093/jn/136.4.1005 | Intervention/Exposure; Sample size/Power
511 | Desroches, S, Chouinard, PY, Galibois, I, et al. Lack of effect of dietary conjugated linoleic acids naturally incorporated into butter on the lipid profile and body composition of overweight and obese men. Am J Clin Nutr. 2005. 82:309-19. doi:10.1093/ajcn.82.2.309 | Comparator; Sample size/Power
512 | Dhillon J, Thorwald M, De La Cruz N, et al. Glucoregulatory and Cardiometabolic Profiles of Almond vs. Cracker Snacking for 8 Weeks in Young Adults: A Randomized Controlled Trial. Nutrients. Jul 25 2018;10(8)doi:10.3390/nu10080960 | Intervention/Exposure
513 | di Giuseppe, R, Bonanni, A, Olivieri, M, et al. Adherence to Mediterranean diet and anthropometric and metabolic parameters in an observational study in the ‘Alto Molise’ region: the MOLI-SAL project. Nutr Metab Cardiovasc Dis. 2008. 18:415-21. doi:10.1016/j.numecd.2007.05.010 | Study design; Intervention/Exposure
514 | di Giuseppe, R, Di Castelnuovo, A, Melegari, C, et al. Typical breakfast food consumption and risk factors for cardiovascular disease in a large sample of Italian adults. Nutr Metab Cardiovasc Dis. Apr 2012;22(4):347-54. doi:10.1016/j.numecd.2010.07.006 | Intervention/Exposure
515 | Di Renzo, GC, Brillo, E, Romanelli, M, et al. Potential effects of chocolate on human pregnancy: a randomized controlled trial. J Matern Fetal Neonatal Med. Oct 2012;25(10):1860-7. doi:10.3109/14767058.2012.683085 | Intervention/Exposure; Comparator
516 | Dias, CB, Amigo, N, Wood, LG, et al. Effect of diets rich in either saturated fat or n-6 polyunsaturated fatty acids and supplemented with long-chain n-3 polyunsaturated fatty acids on plasma lipoprotein profiles. Eur J Clin Nutr. 2017. 71:1297-1302. doi:10.1038/ejcn.2017.56 | Intervention/Exposure; Sample size/Power
517 | Diaz, VA, Mainous, AG, 3rd, Koopman, et al. Race and diet in the overweight: association with cardiovascular risk in a nationally representative sample. Nutrition. 2005. 21:718-25. doi:10.1016/j.nut.2004.11.010 | Study design; Intervention/Exposure
518 | Díaz-López A, Bulló M, Martínez-González MA, et al. Dairy product consumption and risk of type 2 diabetes in an elderly Spanish Mediterranean population at high cardiovascular risk. Eur J Nutr. 2016;55(1):349-360. doi:10.1007/s00394-015-0855-8 | Outcome
519 | Dietary intervention study in children (DISC) with elevated low-density-lipoprotein cholesterol. Design and baseline characteristics. DISC Collaborative Research Group. Ann Epidemiol. 1993;3(4):393-402. doi:10.1016/1047-2797(93)90067-e | Intervention/Exposure
520 | Dikariyanto, V, Berry, SE, Francis, L, et al. Whole almond consumption is associated with better diet quality and cardiovascular disease risk factors in the UK adult population: National Diet and Nutrition Survey (NDNS) 2008-2017. European Journal of Nutrition. Mar 2021;60(2):643-654. doi:10.1007/s00394-020-02270-9 | Study design
521 | Dilis, V, Katsoulis, M, Lagiou, P, et al. Mediterranean diet and CHD: the Greek European Prospective Investigation into Cancer and Nutrition cohort. Br J Nutr. 2012. 108:699-709. doi:10.1017/s0007114512001821 | Intervention/Exposure; Comparator
522 | DiMarco, DM, Norris, GH, Millar, CL, et al Intake of up to 3 Eggs per Day Is Associated with Changes in HDL Function and Increased Plasma Antioxidants in Healthy, Young Adults. Journal of Nutrition. Mar 2017;147(3):323-329. doi:10.3945/jn.116.241877 | Intervention/Exposure
523 | Ding, M, Li, J, Qi, L, et al. Associations of dairy intake with risk of mortality in women and men: three prospective cohort studies. Bmj. 2019. 367:l6204. doi:10.1136/bmj.l6204 | Intervention/Exposure
524 | Ding, N, Wang, X, Tucker, KL, et al. Dietary patterns, bone lead and incident coronary heart disease among middle-aged to elderly men. Environ Res. 2019. 168:222-229. doi:10.1016/j.envres.2018.09.035 | Intervention/Exposure
525 | Dittrich, M, Jahreis, G, Bothor, K, et al. Benefits of foods supplemented with vegetable oils rich in α-linolenic, stearidonic or docosahexaenoic acid in hypertriglyceridemic subjects: a double-blind, randomized, controlled trail. Eur J Nutr. 2015. 54:881-93. doi:10.1007/s00394-014-0764-2 | Intervention/Exposure; Sample size/Power
526 | Dixon, LB, Tershakovec, AM, McKenzie, J, et al. Diet quality of young children who received nutrition education promoting lower dietary fat. Public Health Nutr. Dec 2000;3(4):411-6. doi:10.1017/s1368980000000471 | Intervention/Exposure
527 | Djekic, D, Shi, L, Brolin, H, et al. Effects of a Vegetarian Diet on Cardiometabolic Risk Factors, Gut Microbiota, and Plasma Metabolome in Subjects With Ischemic Heart Disease: a Randomized, Crossover Study. Journal of the American Heart Association. 2020. 9:e016518. doi:10.1161/JAHA.120.016518 | Health status
528 | Djoussé L, Pankow JS, Hunt SC, et al. Influence of saturated fat and linolenic acid on the association between intake of dairy products and blood pressure. Hypertension. 2006;48(2):335-341. doi:10.1161/01.HYP.0000229668.73501.e8 | Intervention/Exposure; Comparator
529 | Djoussé, L, Petrone, AB, Gaziano, JM. Consumption of fried foods and risk of heart failure in the physicians’ health study. J Am Heart Assoc. Apr 23 2015;4(4)doi:10.1161/JAHA.114.001740 | Intervention/Exposure
530 | Djuric, Z, Ren, J, Blythe, J, et al. A Mediterranean dietary intervention in healthy American women changes plasma carotenoids and fatty acids in distinct clusters. Nutr Res. 2009. 29:156-63. doi:10.1016/j.nutres.2009.03.001 | Intervention/Exposure
531 | Do, R, Xie, C, Zhang, X, et al. The Effect of Chromosome 9p21 Variants on Cardiovascular Disease May Be Modified by Dietary Intake: Evidence from a Case/Control and a Prospective Study. Plos Medicine. Oct 2011;8(10)doi:ARTN e1001106 10.1371/journal.pmed.1001106 | Intervention/Exposure
532 | Dobrzyńska, MA, Przysławski, J. The effect of camelina oil (α-linolenic acid) and canola oil (oleic acid) on lipid profile, blood pressure, and anthropometric parameters in postmenopausal women. Arch Med Sci. 2021. 17:1566-1574. doi:10.5114/aoms.2020.94033 | Intervention/Exposure
533 | Does coconut oil improve cholesterol by raising good cholesterol, or should I use fish oil?. Mayo Clinic Health Letter. 2012;30(8):8. | Publication status
534 | Dolecek, TA, Johnson, RL, Grandits, GA, et al. Nutritional adequacy of diets reported at baseline and during trial years 1-6 by the special intervention and usual care groups in the Multiple Risk Factor Intervention Trial. Am J Clin Nutr. 1997. 65:305s-313s. doi:10.1093/ajcn/65.1.305S | Study design; Intervention/Exposure
535 | Dong, JY, Iso, H, Yamagishi, K, et al. Chocolate consumption and risk of stroke among men and women: A large population-based, prospective cohort study. Atherosclerosis. May 2017;260:8-12. doi:10.1016/j.atherosclerosis.2017.03.004 | Intervention/Exposure; Comparator
536 | Dong, S, Zhang, R, Ji, YC, et al. Soy milk powder supplemented with phytosterol esters reduced serum cholesterol level in hypercholesterolemia independently of lipoprotein E genotype: a random clinical placebo-controlled trial. Nutr Res. 2016. 36:879-84. doi:10.1016/j.nutres.2016.05.006 | Intervention/Exposure; Comparator
537 | Dong, X, Zhuang, Z, Zhao, Y, et al. Unprocessed Red Meat and Processed Meat Consumption, Plasma Metabolome, and Risk of Ischemic Heart Disease: A Prospective Cohort Study of UK Biobank. J Am Heart Assoc. 2023. 12:e027934. doi:10.1161/jaha.122.027934 | Intervention/Exposure; Comparator
538 | Doornbos, AM, Meynen, EM, Duchateau, GS, et al. Intake occasion affects the serum cholesterol lowering of a plant sterol-enriched single-dose yoghurt drink in mildly hypercholesterolaemic subjects. Eur J Clin Nutr. Mar 2006;60(3):325-33. doi:10.1038/sj.ejcn.1602318 | Comparator
539 | Dorgan, JF, Liu, L, Barton, BA, et al. Adolescent diet and metabolic syndrome in young women: results of the Dietary Intervention Study in Children (DISC) follow-up study. J Clin Endocrinol Metab. Dec 2011;96(12):E1999-2008. doi:10.1210/jc.2010-2726 | Intervention/Exposure
540 | Dougherty, RM, Allman, MA, Iacono, JM. Effects of diets containing high or low amounts of stearic acid on plasma lipoprotein fractions and fecal fatty acid excretion of men. Am J Clin Nutr. May 1995;61(5):1120-8. doi:10.1093/ajcn/61.4.1120 | Sample size/Power
541 | Drake, I, Sonestedt, E, Ericson, U, et al. A Western dietary pattern is prospectively associated with cardio-metabolic traits and incidence of the metabolic syndrome. Br J Nutr. 2018. 119:1168-1176. doi:10.1017/s000711451800079x | Comparator
542 | Drehmer, M, Pereira, MA, Schmidt, MI, et al. Associations of dairy intake with glycemia and insulinemia, independent of obesity, in Brazilian adults: the Brazilian Longitudinal Study of Adult Health (ELSA-Brasil). Am J Clin Nutr. 2015. 101:775-82. doi:10.3945/ajcn.114.102152 | Outcome
543 | Drehmer, M, Pereira, MA, Schmidt, MI, et al. Total and Full-Fat, but Not Low-Fat, Dairy Product Intakes are Inversely Associated with Metabolic Syndrome in Adults. J Nutr. 2016. 146:81-9. doi:10.3945/jn.115.220699 | Comparator
544 | Dreon, DM, Fernstrom, HA, Miller, B, et al. Low-density lipoprotein subclass patterns and lipoprotein response to a reduced-fat diet in men. FASEB J. Jan 1994;8(1):121-6. | Intervention/Exposure
545 | Dreon, DM, Fernstrom, HA, Williams, PT, et al. LDL subclass patterns and lipoprotein response to a low-fat, high-carbohydrate diet in women. Arterioscler Thromb Vasc Biol. 1997. 17:707-14. doi:10.1161/01.atv.17.4.707 | Intervention/Exposure
546 | Dressler, J, Storz, MA, Müller, C, et al. Does a Plant-Based Diet Stand Out for Its Favorable Composition for Heart Health? Dietary Intake Data from a Randomized Controlled Trial. Nutrients. Nov 1 2022;14(21)doi:10.3390/nu14214597 | Intervention/Exposure; Sample size/Power
547 | Drewnowski, A, Fiddler, EC, Dauchet, L, et al. Diet quality measures and cardiovascular risk factors in France: applying the Healthy Eating Index to the SU.VI.MAX study. J Am Coll Nutr. Feb 2009;28(1):22-9. doi:10.1080/07315724.2009.10719757 | Study design; Intervention/Exposure
548 | Drobner T, Braun TS, Kiehntopf M, Schlattmann P, Lorkowski S, Dawczynski C. Evaluation of Influencing Factors on Metabolism of Land-Based n-3 Poly Unsaturated Fatty Acids-The KoALA Study. Nutrients. 2023;15(20):4461. Published 2023 Oct 20. doi:10.3390/nu15204461 | Comparator; Sample size/Power
549 | Drogan D, Hoffmann K, Schulz M, Bergmann MM, Boeing H, Weikert C. A food pattern predicting prospective weight change is associated with risk of fatal but not with nonfatal cardiovascular disease. J Nutr. 2007;137(8):1961-1967. doi:10.1093/jn/137.8.1961 | Study design; Intervention/Exposure; No confounder adjustment
550 | Drouin-Chartier, J, Tremblay, AJ, Lépine, M, et al. Substitution of dietary ω-6 polyunsaturated fatty acids for saturated fatty acids decreases LDL apolipoprotein B-100 production rate in men with dyslipidemia associated with insulin resistance: a randomized controlled trial. American journal of clinical nutrition. 2018. 107:26-34. doi:10.1093/ajcn/nqx013 | Intervention/Exposure
551 | Drouin-Chartier, JP, Gagnon, J, Labonté, MÈ, et al. Impact of milk consumption on cardiometabolic risk in postmenopausal women with abdominal obesity. Nutr J. 2015. 14:12. doi:10.1186/1475-2891-14-12 | Sample size/Power
552 | Drouin-Chartier, JP, Gigleux, I, Tremblay, AJ, et al. Impact of dairy consumption on essential hypertension: a clinical study. Nutr J. 2014. 13:83. doi:10.1186/1475-2891-13-83 | Intervention/Exposure; Comparator
553 | Drouin-Chartier, JP, Tremblay, AJ, Maltais-Giguère, J, et al. Differential impact of the cheese matrix on the postprandial lipid response: a randomized, crossover, controlled trial. Am J Clin Nutr. 2017. 106:1358-1365. doi:10.3945/ajcn.117.165027 | Duration
554 | Du, H, Guo, Y, Bennett, DA, et al. Red meat, poultry and fish consumption and risk of diabetes: a 9 year prospective cohort study of the China Kadoorie Biobank. Diabetologia. 2020. 63:767-779. doi:10.1007/s00125-020-05091-x | Outcome; Country
555 | Du, R, Cao, H. Dietary pattern associated with C-reactive protein and trajectories of blood pressure in Chinese adults: Evidence from the China Health and Nutrition Survey. J Hum Nutr Diet. 2022. 35:605-612. doi:10.1111/jhn.12978 | Intervention/Exposure
556 | Duane, WC. Effects of legume consumption on serum cholesterol, biliary lipids, and sterol metabolism in humans. J Lipid Res. Jun 1997;38(6):1120-8. | Intervention/Exposure; Sample size/Power
557 | Ducharme-Smith, K, Chambers, R, Garcia-Larsen, V, et al. Native Youth Participating in the Together on Diabetes 12-Month Home-Visiting Program Reported Improvements in Alternative Healthy Eating Index-2010 Diet Quality Domains Likely to Be Associated With Blood Pressure and Glycemic Control. J Acad Nutr Diet. 2021. 121:1125-1135. doi:10.1016/j.jand.2020.12.017 | Intervention/Exposure
558 | Due, A, Larsen, TM, Mu, H, et al. Comparison of 3 ad libitum diets for weight-loss maintenance, risk of cardiovascular disease, and diabetes: A 6-mo randomized, controlled trial. American Journal of Clinical Nutrition. 2008. 88:1232-1241. doi:10.3945/ajcn.2007.25695 | Intervention/Exposure
559 | Duffey, KJ, Davy, BM. The Healthy Beverage Index Is Associated with Reduced Cardiometabolic Risk in US Adults: A Preliminary Analysis. Journal of the Academy of Nutrition and Dietetics. Oct 2015;115(10):1682-1689. doi:10.1016/j.jand.2015.05.005 | Study design; Intervention/Exposure
560 | Duffey, KJ, Gordon-Larsen, P, Steffen, LM, et al. Drinking caloric beverages increases the risk of adverse cardiometabolic outcomes in the Coronary Artery Risk Development in Young Adults (CARDIA) Study. Am J Clin Nutr. Oct 2010;92(4):954-9. doi:10.3945/ajcn.2010.29478 | Intervention/Exposure; Comparator
561 | Duffey, KJ, Steffen, LM, Van Horn, L, et al. Dietary patterns matter: diet beverages and cardiometabolic risks in the longitudinal Coronary Artery Risk Development in Young Adults (CARDIA) Study. Am J Clin Nutr. 2012. 95:909-15. doi:10.3945/ajcn.111.026682 | Intervention/Exposure
562 | Dugan, CE, Aguilar, D, Park, YK, et al. Dairy Consumption Lowers Systemic Inflammation and Liver Enzymes in Typically Low-Dairy Consumers with Clinical Characteristics of Metabolic Syndrome. J Am Coll Nutr. 2016;35(3):255-61. doi:10.1080/07315724.2015.1022637 | Outcome
563 | Dugan, CE, Barona, J, Fernandez, ML. Increased dairy consumption differentially improves metabolic syndrome markers in male and female adults. Metab Syndr Relat Disord. 2014. 12:62-9. doi:10.1089/met.2013.0109 | Intervention/Exposure
564 | Duggan, C, De Dieu Tapsoba, J, Wang, CY, et al. Dietary Weight Loss, Exercise, and Oxidative Stress in Postmenopausal Women: A Randomized Controlled Trial. Cancer Prev Res (Phila). Nov 2016;9(11):835-843. doi:10.1158/1940-6207.CAPR-16-0163 | Intervention/Exposure
565 | Duijzer, G, Haveman-Nies, A, Jansen, SC, et al. Effect and maintenance of the SLIMMER diabetes prevention lifestyle intervention in Dutch primary healthcare: a randomised controlled trial. Nutr Diabetes. May 8 2017;7(5):e268. doi:10.1038/nutd.2017.21 | Intervention/Exposure
566 | Dunne, S, McGillicuddy, FC, Gibney, ER, et al. Role of food matrix in modulating dairy fat induced changes in lipoprotein particle size distribution in a human intervention. Am J Clin Nutr. 2023. 117:111-120. doi:10.1016/j.ajcnut.2022.10.002 | Comparator
567 | D’Urso S, Hwang LD. New Insights into Polygenic Score-Lifestyle Interactions for Cardiometabolic Risk Factors from Genome-Wide Interaction Analyses. Nutrients. 2023;15(22):4815. doi:10.3390/nu15224815 | Intervention/Exposure
568 | Dwyer, JH, Dwyer, KM, Scribner, RA, et al. Dietary calcium, calcium supplementation, and blood pressure in African American adolescents. Am J Clin Nutr. Sep 1998;68(3):648-55. doi:10.1093/ajcn/68.3.648 | Intervention/Exposure
569 | Eady, S, Wallace, A, Willis, J, et al. Consumption of a plant sterol-based spread derived from rice bran oil is effective at reducing plasma lipid levels in mildly hypercholesterolaemic individuals. Br J Nutr. 2011. 105:1808-18. doi:10.1017/s0007114510005519 | Intervention/Exposure; Comparator
570 | Eaton CB. Can reduced or modified dietary fat prevent cardiovascular disease?. Am Fam Physician. 2002;65(1):53-55. | Study design
571 | Ebbeling, CB, Klein, GL, Luoto, PK, et al. A randomized study of dietary composition during weight-loss maintenance: rationale, study design, intervention, and assessment. Contemporary clinical trials. 2018. 65:76-86. doi:10.1016/j.cct.2017.12.004 | Intervention/Exposure
572 | Ebbeling, CB, Knapp, A, Johnson, A, et al. Effects of a low-carbohydrate diet on insulin-resistant dyslipoproteinemia-a randomized controlled feeding trial. Am J Clin Nutr. 2022. 115:154-162. doi:10.1093/ajcn/nqab287 | Intervention/Exposure
573 | Ebbeling, CB, Leidig, MM, Sinclair, KB, et al. Effects of an ad libitum low-glycemic load diet on cardiovascular disease risk factors in obese young adults. Am J Clin Nutr. 2005. 81:976-82. doi:10.1093/ajcn/81.5.976 | Intervention/Exposure; Sample size/Power
574 | Ebrahimof, S, Hosseini-Esfahani, F, Mirmiran, P, et al. Food Patterns and Framingham Risk Score in Iranian Adults: Tehran Lipid and Glucose Study: 2005-2011. Metab Syndr Relat Disord. Feb 2018;16(1):64-71. doi:10.1089/met.2017.0125 | Intervention/Exposure
575 | Edionwe, AO, Kies, C. Comparison of palm, palmstearin, palmolein, and partially hydrogenated soybean oils: effects on serum lipids and fecal fatty acid excretions of adult humans. International Journal of Food Sciences and Nutrition. Nov 1998;49(6):477-483. doi:Doi 10.3109/09637489809086428 | Sample size/Power
576 | Egert, S, Kratz, M, Kannenberg, F, et al. Effects of high-fat and low-fat diets rich in monounsaturated fatty acids on serum lipids, LDL size and indices of lipid peroxidation in healthy non-obese men and women when consumed under controlled conditions. European Journal of Nutrition. Feb 2011;50(1):71-79. doi:10.1007/s00394-010-0116-9 | Intervention/Exposure; Sample size/Power
577 | Eguchi, E, Iso, H, Honjo, K, et al. No modifying effect of education level on the association between lifestyle behaviors and cardiovascular mortality: the Japan Collaborative Cohort Study. Sci Rep. 2017. 7:39820. doi:10.1038/srep39820 | Intervention/Exposure
578 | Eguchi, E, Iso, H, Tanabe, N, et al. Healthy lifestyle behaviours and cardiovascular mortality among Japanese men and women: the Japan collaborative cohort study. Eur Heart J. 2012. 33:467-77. doi:10.1093/eurheartj/ehr429 | Intervention/Exposure; Comparator
579 | Eguchi, E, Iso, H, Tanabe, N, et al. Is the association between healthy lifestyle behaviors and cardiovascular mortality modified by overweight status? The Japan Collaborative Cohort Study. Prev Med. 2014. 62:142-7. doi:10.1016/j.ypmed.2013.12.004 | Intervention/Exposure
580 | Eisenberg, D. Plant sterols are efficacious in lowering plasma cholesterol. Curr Atheroscler Rep. Jan 2006;8(1):53. doi:10.1007/s11883-006-0064-2 | Study design; Publication status
581 | Elkan, AC, Anania, C, Gustafsson, T, et al. Diet and fatty acid pattern among patients with SLE: associations with disease activity, blood lipids and atherosclerosis. Lupus. Nov 2012;21(13):1405-1411. doi:10.1177/0961203312458471 | Health status
582 | Ellingsen, I, Hjerkinn, EM, Arnesen, H, et al. Follow-up of diet and cardiovascular risk factors 20 years after cessation of intervention in the Oslo Diet and Antismoking Study. Eur J Clin Nutr. Mar 2006;60(3):378-85. doi:10.1038/sj.ejcn.1602327 | Intervention/Exposure
583 | Elliott, LJ, Keown-Stoneman, CDG, Birken, CS, et al. Vegetarian Diet, Growth, and Nutrition in Early Childhood: A Longitudinal Cohort Study. Pediatrics. Jun 1 2022;149(6)doi:10.1542/peds.2021-052598 | Intervention/Exposure; Comparator
584 | Elmer, PJ, Obarzanek, E, Vollmer, WM, et al. Effects of comprehensive lifestyle modification on diet, weight, physical fitness, and blood pressure control: 18-month results of a randomized trial. Ann Intern Med. Apr 4 2006;144(7):485-95. doi:10.7326/0003-4819-144-7-200604040-00007 | Intervention/Exposure
585 | Eloranta, AM, Lindi, V, Schwab, U, et al. Dietary factors associated with metabolic risk score in Finnish children aged 6-8 years: the PANIC study. Eur J Nutr. Sep 2014;53(6):1431-9. doi:10.1007/s00394-013-0646-z | Study design
586 | Elwood, PC, Pickering, JE, Fehily, AM, et al. Milk drinking, ischaemic heart disease and ischaemic stroke I. Evidence from the Caerphilly cohort. Eur J Clin Nutr. 2004. 58:711-7. doi:10.1038/sj.ejcn.1601868 | Intervention/Exposure; Comparator
587 | Elwood, PC, Pickering, JE, Fehily, AM. Milk and dairy consumption, diabetes and the metabolic syndrome: the Caerphilly prospective study. J Epidemiol Community Health. 2007. 61:695-8. doi:10.1136/jech.2006.053157 | Outcome
588 | Elwood, PC, Strain, JJ, Robson, PJ, et al. Milk consumption, stroke, and heart attack risk: evidence from the Caerphilly cohort of older men. J Epidemiol Community Health. 2005. 59:502-5. doi:10.1136/jech.2004.027904 | Intervention/Exposure; Comparator
589 | Engberink, MF, Geleijnse, JM, de Jong, N, et al. Dairy intake, blood pressure, and incident hypertension in a general Dutch population. J Nutr. Mar 2009;139(3):582-7. doi:10.3945/jn.108.093088 | Comparator
590 | Engberink, MF, Geleijnse, JM, Wanders, AJ, et al. The effect of conjugated linoleic acid, a natural trans fat from milk and meat, on human blood pressure: results from a randomized crossover feeding study. J Hum Hypertens. Feb 2012;26(2):127-32. doi:10.1038/jhh.2010.132 | Duration
591 | Engberink, MF, Hendriksen, MA, Schouten, EG, et al. Inverse association between dairy intake and hypertension: the Rotterdam Study. Am J Clin Nutr. 2009. 89:1877-83. doi:10.3945/ajcn.2008.27064 | Comparator
592 | Engel, S, Tholstrup, T, Bruun, JM, et al. Effect of high milk and sugar-sweetened and non-caloric soft drink intake on insulin sensitivity after 6 months in overweight and obese adults: a randomized controlled trial. Eur J Clin Nutr. Mar 2018;72(3):358-366. doi:10.1038/s41430-017-0006-9 | Sample size/Power
593 | Engelberts, I, Sundram, K, Van Houwelingen, AC, et al. The effect of replacement of dietary fat by palm oil on in vitro cytokine release. Article. Br J Nutr. Jan 1993;69(1):159-67. doi:10.1079/bjn19930018 | Outcome; Comparator
594 | Engelfriet, P, Hoekstra, J, Hoogenveen, R, et al. Food and vessels: the importance of a healthy diet to prevent cardiovascular disease. Eur J Cardiovasc Prev Rehabil. Feb 2010;17(1):50-5. doi:10.1097/HJR.0b013e32832f3a76 | Study design; Intervention/Exposure
595 | Engler, MB, Engler, MM. The emerging role of flavonoid-rich cocoa and chocolate in cardiovascular health and disease. Nutr Rev. Mar 2006;64(3):109-18. doi:10.1111/j.1753-4887.2006.tb00194.x | Study design
596 | Entwistle, MR, Schweizer, D, Cisneros, R. Dietary patterns related to total mortality and cancer mortality in the United States. Cancer Causes and Control. 2021. 32:1279-1288. doi:10.1007/s10552-021-01478-2 | Intervention/Exposure
597 | Ericson, U, Brunkwall, L, Alves Dias, J, et al. Food patterns in relation to weight change and incidence of type 2 diabetes, coronary events and stroke in the Malmö Diet and Cancer cohort. Eur J Nutr. 2019. 58:1801-1814. doi:10.1007/s00394-018-1727-9 | Intervention/Exposure
598 | Erkkilä, AT, Schwab, US, de Mello, VD, et al Effects of fatty and lean fish intake on blood pressure in subjects with coronary heart disease using multiple medications. Eur J Nutr. Sep 2008;47(6):319-28. doi:10.1007/s00394-008-0728-5 | Health status
599 | Erlinger, TP, Miller, ER, 3rd, Charleston, et al. Inflammation modifies the effects of a reduced-fat low-cholesterol diet on lipids: results from the DASH-sodium trial. Circulation. Jul 15 2003;108(2):150-4. doi:10.1161/01.CIR.0000080288.30567.86 | Intervention/Exposure
600 | Escurriol, V, Cofán, M, Serra, M, et al. Serum sterol responses to increasing plant sterol intake from natural foods in the Mediterranean diet. Eur J Nutr. 2009. 48:373-82. doi:10.1007/s00394-009-0024-z | Intervention/Exposure
601 | Esfahani, A, Jenkins, DJ, Kendall, CW. Session 4: CVD, diabetes and cancer: A dietary portfolio for management and prevention of heart disease. Proc Nutr Soc. 2010. 69:39-44. doi:10.1017/s0029665109991777 | Study design; Publication status
602 | Esfandiar, Z, Hosseini-Esfahani, F, Mirmiran, P, et al. Red meat and dietary iron intakes are associated with some components of metabolic syndrome: Tehran Lipid and Glucose Study. J Transl Med. 2019. 17:313. doi:10.1186/s12967-019-2059-0 | Comparator
603 | Eshel, G, Shepon, A, Noor, E, et al. Environmentally Optimal, Nutritionally Aware Beef Replacement Plant-Based Diets. Environmental Science and Technology. 2016. 50:8164-8168. doi:10.1021/acs.est.6b01006 | Study design
604 | Eshriqui, I, Franco-Sena, AB, Farias, DR, et al. Prepregnancy Dietary Patterns Are Associated with Blood Lipid Level Changes During Pregnancy: A Prospective Cohort Study in Rio de Janeiro, Brazil. J Acad Nutr Diet. 2017. 117:1066-1079.e1. doi:10.1016/j.jand.2016.12.007 | Intervention/Exposure
605 | Eslami, O, Shidfar, F, Maleki, Z, et al. Effect of Soy Milk on Metabolic Status of Patients with Nonalcoholic Fatty Liver Disease: A Randomized Clinical Trial. J Am Coll Nutr. Jan 2019;38(1):51-58. doi:10.1080/07315724.2018.1479990 | Intervention/Exposure; Health status; Comparator
606 | Esrey, KL, Joseph, L, Grover, SA. Relationship between dietary intake and coronary heart disease mortality: lipid research clinics prevalence follow-up study. J Clin Epidemiol. 1996. 49:211-6. doi:10.1016/0895-4356(95)00066-6 | Intervention/Exposure
607 | Estévez-González, MD, Saavedra-Santana, P, López-Ríos, L, et al. HDL cholesterol levels in children with mild hypercholesterolemia: effect of consuming skim milk enriched with olive oil and modulation by the TAQ 1B polymorphism in the CETP gene. Ann Nutr Metab. 2010. 56:288-93. doi:10.1159/000290405 | Comparator
608 | Eussen, SR, de Jong, N, Rompelberg, CJ, et al. Dose-dependent cholesterol-lowering effects of phytosterol/phytostanol-enriched margarine in statin users and statin non-users under free-living conditions. Public Health Nutr. 2011. 14:1823-32. doi:10.1017/s1368980011000164 | Intervention/Exposure
609 | Evans, AE, Ruidavets, JB, McCrum, EE, et al. Autres pays, autres coeurs? Dietary patterns, risk factors and ischaemic heart disease in Belfast and Toulouse. QJM. Jul 1995;88(7):469-77. | Intervention/Exposure; Outcome
610 | Ewers, B, Marott, JL, Schnohr, P, et al. Non-adherence to established dietary guidelines associated with increased mortality: The Copenhagen General Population Study. European Journal of Preventive Cardiology. 2021. 28:1259-1268. doi:10.1177/2047487320937491 | Intervention/Exposure
611 | Faghih S, Hedayati M, Abadi A, Kimiagar M. Comparing the effects of cow’s milk, and calcium supplementation on components of the metabolic syndrome in overweight or obese women. Iranian Journal of Endocrinology and Metabolism. 2013;14(5): 430-436. | Comparator; Sample size/Power
612 | Fan B, Huang X, Zhao JV. Exploration of Metabolic Biomarkers Linking Red Meat Consumption to Ischemic Heart Disease Mortality in the UK Biobank. Nutrients. 2023;15(8):1865. Published 2023 Apr 13. doi:10.3390/nu15081865 | Intervention/Exposure
613 | Fan, B, Zhao, JV. Sex-Specific Associations of Red Meat and Processed Meat Consumption with Serum Metabolites in the UK Biobank. Nutrients. Dec 14 2022;14(24)doi:10.3390/nu14245306 | Comparator
614 | Fan, H, Wang, Y, Ren, Z, et al. Mediterranean diet lowers all-cause and cardiovascular mortality for patients with metabolic syndrome. Diabetol Metab Syndr. 2023. 15:107. doi:10.1186/s13098-023-01052-7 | Comparator
615 | Farchi G, Fidanza F, Mariotti S, Menotti A. Is diet an independent risk factor for mortality? 20 year mortality in the Italian rural cohorts of the Seven Countries Study. Eur J Clin Nutr. 1994;48(1):19-29. | Intervention/Exposure
616 | Farchi, G, Fidanza, F, Grossi, P, et al. Relationship between Eating Patterns Meeting Recommendations and Subsequent Mortality in 20 Years. European Journal of Clinical Nutrition. Jun 1995;49(6):408-419. | Intervention/Exposure
617 | Fard, NM, Mehrabian, F, Sarraf-Zadegan, N, et al. Fat-modified diets during pregnancy and lactation and serum lipids after birth. Indian J Pediatr. 2004. 71:683-7. doi:10.1007/bf02730653 | Intervention/Exposure; Country
618 | Faridi, Z, Njike, VY, Dutta, S, et al. Acute dark chocolate and cocoa ingestion and endothelial function: a randomized controlled crossover trial. Am J Clin Nutr. 2008. 88:58-63. doi:10.1093/ajcn/88.1.58 | Intervention/Exposure; Sample size/Power
619 | Farnsworth, E, Luscombe, ND, Noakes, M, et al Effect of a high-protein, energyrestricted diet on body composition, glycemic control, and lipid concentrations in overweight and obese hyperinsulinemic men and women. Am J Clin Nutr. Jul 2003;78(1):31-9. doi:10.1093/ajcn/78.1.31 | Intervention/Exposure; Comparator
620 | Farvid, MS, Malekshah, AF, Pourshams, A, et al. Dairy Food Intake and All-Cause, Cardiovascular Disease, and Cancer Mortality: The Golestan Cohort Study. Am J Epidemiol. 2017. 185:697-711. doi:10.1093/aje/kww139 | Comparator
621 | Farvid, MS, Malekshah, AF, Pourshams, A, et al. Dietary Protein Sources and All-Cause and Cause-Specific Mortality: The Golestan Cohort Study in Iran. Am J Prev Med. 2017. 52:237-248. doi:10.1016/j.amepre.2016.10.041 | Intervention/Exposure; Comparator
622 | Farzanegi P, Samiee M, Sabbaghian Z. Interactive effect of regular aerobic training and milk consumption consumption on some inflammatory markers and lipid profile in overweight boys. Koomesh Journal. 2016;17(3):627-635. | Publication language
623 | Fathi, Y, Ghodrati, N, Zibaeenezhad, MJ, et al. Kefir drink causes a significant yet similar improvement in serum lipid profile, compared with low-fat milk, in a dairy-rich diet in overweight or obese premenopausal women: A randomized controlled trial. J Clin Lipidol. 2017. 11:136-146. doi:10.1016/j.jacl.2016.10.016 | Comparator; Sample size/Power
624 | Fechner, E, Bilet, L, Peters, HPF, et al. A Whole-Diet Approach Affects Not Only Fasting but Also Postprandial Cardiometabolic Risk Markers in Overweight and Obese Adults: A Randomized Controlled Trial. J Nutr. 2020. 150:2942-2949. doi:10.1093/jn/nxaa252 | Intervention/Exposure; Sample size/Power
625 | Feeney, EL, Barron, R, Dible, V, et al. Dairy matrix effects: response to consumption of dairy fat differs when eaten within the cheese matrix-a randomized controlled trial. American journal of clinical nutrition. 2018. 108:667-674. doi:10.1093/ajcn/nqy146 | Intervention/Exposure; Comparator
626 | Fehily, AM, Pickering, JE, Yarnell, JW, et al. Dietary indices of atherogenicity and thrombogenicity and ischaemic heart disease risk: the Caerphilly Prospective Study. Br J Nutr. Feb 1994;71(2):249-57. doi:10.1079/bjn19940131 | Intervention/Exposure
627 | Fehily, AM, Yarnell, JW, Sweetnam, PM, et al. Diet and incident ischaemic heart disease: the Caerphilly Study. Br J Nutr. Mar 1993;69(2):303-14. doi:10.1079/bjn19930035 | Intervention/Exposure
628 | Feidantsis, K, Methenitis, S, Ketselidi, K, et al. Comparison of short-term hypocaloric high-protein diets with a hypocaloric Mediterranean diet: Effect on body composition and health-related blood markers in overweight and sedentary young participants. Nutrition. Nov-Dec 2021;91-92:111365. doi:10.1016/j.nut.2021.111365 | Intervention/Exposure; Sample size/Power
629 | Feranil, AB, Duazo, PL, Kuzawa, CW, et al. Coconut oil is associated with a beneficial lipid profile in pre-menopausal women in the Philippines. Asia Pac J Clin Nutr. 2011;20(2):190-5. | Study design; Country
630 | Ferland, A, Lamarche, B, Château-Degat, ML, et al. Dairy product intake and its association with body weight and cardiovascular disease risk factors in a population in dietary transition. J Am Coll Nutr. Apr 2011;30(2):92-9. doi:10.1080/07315724.2011.10719948 | Study design
631 | Fernández De La Puebla, RA, Carmona, J, Fuentes, F, et al. [Response degree of cholesterol LDL to feeding in males with hypercholesterolemia according to baseline value]. Med Clin (Barc). May 25 2002;118(19):737-40. Grado de respuesta del colesterol LDL a la alimentacion en varones con hipercolesterolemia segun sus valores basales. | Publication language
632 | Fernández de la Puebla, RA, Fuentes, F, Pérez-Martinez, P, et al. A reduction in dietary saturated fat decreases body fat content in overweight, hypercholesterolemic males. Nutr Metab Cardiovasc Dis. Oct 2003;13(5):273-7. doi:10.1016/s09394753(03)80031-5 | Intervention/Exposure
633 | Fernandez, CA, Potts, K, Bazzano, LA. Effect of ideal protein versus low-fat diet for weight loss: A randomized controlled trial. Obes Sci Pract. 2022. 8:299-307. doi:10.1002/osp4.567 | Intervention/Exposure
634 | Fernando, I, Schmidt, KA, Cromer, G, et al. The impact of low-fat and full-fat dairy foods on symptoms of gastroesophageal reflux disease: an exploratory analysis based on a randomized controlled trial. Eur J Nutr. Aug 2022;61(5):2815-2823. doi:10.1007/s00394-022-02855-6 | Outcome
635 | Ferrara, LA, Raimondi, AS, d’Episcopo, L, et al. Olive oil and reduced need for antihypertensive medications. Arch Intern Med. Mar 27 2000;160(6):837-42. doi:10.1001/archinte.160.6.837 | Sample size/Power
636 | Ferrara, LA, Ricci, F, Viola, S, et al. Dietary pattern and blood pressure control in a hypertension outpatient clinic. Hypertension Research. 2007. 30:1043-1050. doi:10.1291/hypres.30.1043 | Study design
637 | Ferreira, NL, Rodrigues, MTG, Abreu, MNS, et al. [Nutritional factors associated with dyslipidemia in users of service in primary health care]. Acta Med Port. Dec 2011;24 Suppl 2:457-66. Fatores nutricionais associados as dislipidemias em usuarios de servico de atencao primaria a saude. | Publication language
638 | Ferreira, SR, Lerario, DD, Gimeno, SG, et al. Obesity and central adiposity in Japanese immigrants: role of the Western dietary pattern. J Epidemiol. 2002. 12:431-8. doi:10.2188/jea.12.431 | Study design; Country
639 | Ferretti, A, Meydani, SN, Lichtenstein, AH, et al. Prostaglandin-E Metabolite Excretion in Normolipidemic Subjects Is Lowered by a Moderate Reduction of N-6/N-3 Polyunsaturate Ratio and Total Fat Intake. Nutrition Research. Feb 1994;14(2):185-193. doi:Doi 10.1016/S0271-5317(05)80378-1 | Intervention/Exposure
640 | Ferro, Y, Mazza, E, Salvati, M, et al. Effects of a Portfolio-Mediterranean Diet and a Mediterranean Diet with or without a Sterol-Enriched Yogurt in Individuals with Hypercholesterolemia. Endocrinol Metab (Seoul). 2020. 35:298-307. doi:10.3803/EnM.2020.35.2.298 | Intervention/Exposure
641 | Fielding, CJ, Havel, RJ, Todd, KM, et al. Effects of dietary cholesterol and fat saturation on plasma lipoproteins in an ethnically diverse population of healthy young men. J Clin Invest. Feb 1995;95(2):611-8. doi:10.1172/JCI117705 | Intervention/Exposure; Sample size/Power
642 | Fleet JC. DASH without the dash (of salt) can lower blood pressure. Nutr Rev. 2001;59(9):291-293. doi:10.1111/j.1753-4887.2001.tb07019.x | Study design
643 | Fleming, JA, Kris-Etherton, PM, Petersen, KS, et al. Effect of varying quantities of lean beef as part of a Mediterranean-style dietary pattern on lipids and lipoproteins: a randomized crossover controlled feeding trial. Am J Clin Nutr. 2021. 113:1126-1136. doi:10.1093/ajcn/nqaa375 | Intervention/Exposure
644 | Fleming, RM. The effect of high-, moderate-, and low-fat diets on weight loss and cardiovascular disease risk factors. Prev Cardiol. Summer 2002;5(3):110-8. doi:10.1111/j.1520-037x.2002.01231.x | Intervention/Exposure; Sample size/Power
645 | Flynn, MA, Nolph, GB, Sun, GY, et al. Effects of Cholesterol and Fat Modification of Self-Selected Diets on Serum-Lipids and Their Specific Fatty-Acids in Normocholesterolemic and Hypercholesterolemic Humans. Journal of the American College of Nutrition. Apr 1991;10(2):93-106. | Intervention/Exposure
646 | Flynn, MM, Zmuda, JM, Milosavljevic, D, et al. Lipoprotein response to a national cholesterol education program step II diet with and without energy restriction. Metabolism-Clinical and Experimental. Jul 1999;48(7):822-826. doi:Doi 10.1016/S0026-0495(99)90212-3 | Sample size/Power
647 | Foley M, Ball M, Chisholm A, Duncan A, Spears G, Mann J. Should mono- or poly-unsaturated fats replace saturated fat in the diet?. Eur J Clin Nutr. 1992;46(6):429-436. | Intervention/Exposure; Sample size/Power
648 | Fonollá, J, López-Huertas, E, Machado, FJ, et al. Milk enriched with “healthy fatty acids" improves cardiovascular risk markers and nutritional status in human volunteers. Nutrition. 2009. 25:408-14. doi:10.1016/j.nut.2008.10.008 | Intervention/Exposure; Comparator
649 | Fonolla-Joya, J, Reyes-García, R, García-Martín, A, et al. Daily Intake of Milk Enriched with n-3 Fatty Acids, Oleic Acid, and Calcium Improves Metabolic and Bone Biomarkers in Postmenopausal Women. J Am Coll Nutr. Aug 2016;35(6):529-536. doi:10.1080/07315724.2014.1003114 | Intervention/Exposure
650 | Fonseca, MJ, Gaio, R, Lopes, C, et al. Association between dietary patterns and metabolic syndrome in a sample of Portuguese adults. Nutr J. 2012. 11:64. doi:10.1186/1475-2891-11-64 | Study design; Intervention/Exposure
651 | Foraker, RE, Pennell, M, Sprangers, P, et al. Effect of a Low-Fat or Low-Carbohydrate Weight-Loss Diet on Markers of Cardiovascular Risk Among Premenopausal Women: A Randomized Trial. Journal of Womens Health. Aug 2014;23(8):675-680. doi:10.1089/jwh.2013.4638 | Intervention/Exposure
652 | Formisano, E, Pasta, A, Cremonini, AL, et al. Effects of a Mediterranean Diet, Dairy, and Meat Products on Different Phenotypes of Dyslipidemia: A Preliminary Retrospective Analysis. Nutrients. 2021. 13:1161. doi:10.3390/nu13041161 | Study design
653 | Foroozanfard, F, Rafiei, H, Samimi, M, et al. The effects of dietary approaches to stop hypertension diet on weight loss, anti-Mullerian hormone and metabolic profiles in women with polycystic ovary syndrome: A randomized clinical trial. Clin Endocrinol (Oxf). Jul 2017;87(1):51-58. doi:10.1111/cen.13333 | Intervention/Exposure; Health status
654 | Forsythe, CE, Phinney, SD, Feinman, RD, et al. Limited effect of dietary saturated fat on plasma saturated fat in the context of a low carbohydrate diet. Lipids. 2010. 45:947-62. doi:10.1007/s11745-010-3467-3 | Sample size/Power
655 | Foshati, S, Ghanizadeh, A, Akhlaghi, M. The effect of extra virgin olive oil on anthropometric indices, lipid profile, and markers of oxidative stress and inflammation in patients with depression, a double-blind randomised controlled trial. Int J Clin Pract. Jul 2021;75(7):e14254. doi:10.1111/ijcp.14254 | Intervention/Exposure; Health status; Comparator
656 | Foster, HME, Celis-Morales, CA, Nicholl, BI, et al. The effect of socioeconomic deprivation on the association between an extended measurement of unhealthy lifestyle factors and health outcomes: a prospective analysis of the UK Biobank cohort. Lancet Public Health. 2018. 3:e576-e585. doi:10.1016/s2468-2667(18)30200-7 | Intervention/Exposure
657 | Foulkes, S, Kukuljan, S, Nowson, CA, et al. Effects of a multi-modal resistance exercise program and calcium-vitamin D(3) fortified milk on blood pressure and blood lipids in middle-aged and older men: secondary analysis of an 18-month factorial design randomised controlled trial. Eur J Nutr. Apr 2021;60(3):1289-1299. doi:10.1007/s00394-020-02325-x | Intervention/Exposure; Comparator
658 | Frahnow, T, Osterhoff, MA, Hornemann, S, et al. Heritability and responses to high fat diet of plasma lipidomics in a twin study. Sci Rep. 2017. 7:3750. doi:10.1038/s41598-017-03965-6 | Intervention/Exposure
659 | Francis J, Priya J, Devi G. Effect of dark chocolate on blood pressure in patients with hypertension. International Journal of Pharmaceutical Research. 2020; S2:4156-4162. | Study design
660 | Fransen, HP, de Jong, N, Wolfs, M, et al. Customary use of plant sterol and plant stanol enriched margarine is associated with changes in serum plant sterol and stanol concentrations in humans. J Nutr. 2007. 137:1301-6. doi:10.1093/jn/137.5.1301 | Intervention/Exposure; Comparator
661 | Fraser GE, Sabaté J, Beeson WL, Strahan TM. A possible protective effect of nut consumption on risk of coronary heart disease. The Adventist Health Study. Arch Intern Med. 1992;152(7):1416-1424. | Comparator
662 | Fraser, GE, Shavlik, DJ. Risk factors for all-cause and coronary heart disease mortality in the oldest-old. The Adventist Health Study. Arch Intern Med. Oct 27 1997;157(19):2249-58. | Comparator
663 | Fraser, GE. Associations between diet and cancer, ischemic heart disease, and all-cause mortality in non-Hispanic white California Seventh-day Adventists. American Journal of Clinical Nutrition. Sep 1999;70(3):532s-538s. | Intervention/Exposure; Comparator
664 | Frassetto LA, Schloetter M, Mietus-Synder M, Morris RC Jr, Sebastian A. Metabolic and physiologic improvements from consuming a paleolithic, hunter-gatherer type diet [published correction appears in Eur J Clin Nutr. 2015 Dec;69(12):1376. doi: 10.1038/ejcn.2015.193]. Eur J Clin Nutr. 2009;63(8):947-955. doi:10.1038/ejcn.2009.4 | Duration; Sample size/Power
665 | Freire, RD, Cardoso, MA, Gimeno, SGA, et al. Dietary fat is associated with metabolic syndrome in Japanese Brazilians. Diabetes Care. Jul 2005;28(7):1779-1785. doi:DOI 10.2337/diacare.28.7.1779 | Intervention/Exposure
666 | Fresán, U, Martínez-González, MA, Segovia-Siapco, G, et al. A three-dimensional dietary index (nutritional quality, environment and price) and reduced mortality: The “Seguimiento Universidad de Navarra" cohort. Prev Med. 2020. 137:106124. doi:10.1016/j.ypmed.2020.106124 | Intervention/Exposure
667 | Fresán, U, Sabaté, J, Martínez-Gonzalez, MA, et al. Adherence to the 2015 Dietary Guidelines for Americans and mortality risk in a Mediterranean cohort: The SUN project. Prev Med. 2019. 118:317-324. doi:10.1016/j.ypmed.2018.11.015 | Intervention/Exposure
668 | Friedl KE, Klicka MV, King N, Marchitelli LJ, Askew EW. Effects of reduced fat intake on serum lipids in healthy young men and women at the U.S. Military Academy. Mil Med. 1995;160(10):527-533. | Study design; Intervention/Exposure; Publication status
669 | Frisch, S, Zittermann, A, Berthold, HK, et al. A randomized controlled trial on the efficacy of carbohydrate-reduced or fat-reduced diets in patients attending a telemedically guided weight loss program. Article. Cardiovasc Diabetol. Jul 18 2009;8:36. doi:10.1186/1475-2840-8-36 | Intervention/Exposure
670 | Frölich, S, Lehmann, N, Weyers, S, et al. Association of dietary patterns with five-year degree and progression of coronary artery calcification in the Heinz Nixdorf Recall study. Nutr Metab Cardiovasc Dis. 2017. 27:999-1007. doi:10.1016/j.numecd.2017.09.002 | Intervention/Exposure
671 | Fuentes, F, López-Miranda, J, Pérez-Martínez, P, et al. Chronic effects of a high-fat diet enriched with virgin olive oil and a low-fat diet enriched with alpha-linolenic acid on postprandial endothelial function in healthy men. Br J Nutr. 2008. 100:159-65. doi:10.1017/s0007114508888708 | Sample size/Power
672 | Fuentes, F, López-Miranda, J, Sánchez, E, et al Mediterranean and low-fat diets improve endothelial function in hypercholesterolemic men. Ann Intern Med. Jun 19 2001;134(12):1115-9. doi:10.7326/0003-4819-134-12-200106190-00011 | Intervention/Exposure
673 | Fumeron F, Brigant L, Parra HJ, Bard JM, Fruchart JC, Apfelbaum M. Lowering of HDL2-cholesterol and lipoprotein A-I particle levels by increasing the ratio of polyunsaturated to saturated fatty acids. Am J Clin Nutr. 1991;53(3):655-659. doi:10.1093/ajcn/53.3.655 | Duration; Sample size/Power
674 | Fumeron, F, Lamri, A, Abi Khalil, C, et al. Dairy consumption and the incidence of hyperglycemia and the metabolic syndrome: Results from a French prospective study, data from the epidemiological study on the insulin resistance syndrome (DESIR). Diabetes Care. 2011. 34:813-817. doi:10.2337/dc10-1772 | Comparator
675 | Fumeron, F, Lamri, A, Emery, N, et al. Dairy products and the metabolic syndrome in a prospective study, DESIR. J Am Coll Nutr. Oct 2011;30(5 Suppl 1):454S-63S. doi:10.1080/07315724.2011.10719990 | Intervention/Exposure; Comparator
676 | Fumeron, F, Nicolas, A, Bastard, JP, et al. Dairy consumption is associated with lower plasma dihydroceramides in women from the D.E.S.I.R. cohort. Diabetes Metab. 2020. 46:144-149. doi:10.1016/j.diabet.2019.06.002 | Outcome
677 | Fung, TT, Chiuve, SE, McCullough, ML, et al. Adherence to a DASH-style diet and risk of coronary heart disease and stroke in women. Arch Intern Med. Apr 14 2008;168(7):713-20. doi:10.1001/archinte.168.7.713 | Intervention/Exposure
678 | Fung, TT, Rimm, EB, Spiegelman, D, et al. Association between dietary patterns and plasma biomarkers of obesity and cardiovascular disease risk. Am J Clin Nutr. 2001. 73:61-7. doi:10.1093/ajcn/73.1.61 | Intervention/Exposure
679 | Fung, TT, Stampfer, MJ, Manson, JE, et al. Prospective study of major dietary patterns and stroke risk in women. Stroke. Sep 2004;35(9):2014-9. doi:10.1161/01.STR.0000135762.89154.92 | Intervention/Exposure
680 | Fung, TT, van Dam, RM, Hankinson, SE, et al. Low-carbohydrate diets and all-cause and cause-specific mortality: two cohort studies. Ann Intern Med. 2010. 153:289-98. doi:10.7326/0003-4819-153-5-201009070-00003 | Intervention/Exposure
681 | Fung, TT, Willett, WC, Stampfer, MJ, et al. Dietary patterns and the risk of coronary heart disease in women. Arch Intern Med. 2001. 161:1857-62. doi:10.1001/archinte.161.15.1857 | Intervention/Exposure
682 | Furtado, JD, Campos, H, Appel, LJ, et al. Effect of protein, unsaturated fat, and carbohydrate intakes on plasma apolipoprotein B and VLDL and LDL containing apolipoprotein C-III: results from the OmniHeart Trial. Am J Clin Nutr. Jun 2008;87(6):1623-30. doi:10.1093/ajcn/87.6.1623 | Intervention/Exposure
683 | Furuncuoglu, Y, Basar, M, Alıcı, S, et al. Effects of a Stanol-Enriched Yogurt on Plasma Cholesterol Levels. European Journal of General Medicine. 2014;11(4):230-234. doi:10.15197/sabad.1.11.77 | Comparator
684 | Gadelha, Pcfp, de Arruda, IKG, Coelho, PBP, et al. Consumption of ultraprocessed foods, nutritional status, and dyslipidemia in schoolchildren: a cohort study. Eur J Clin Nutr. Aug 2019;73(8):1194-1199. doi:10.1038/s41430-019-0404-2 | Intervention/Exposure
685 | Gadgil, MD, Appel, LJ, Yeung, E, et al. The effects of carbohydrate, unsaturated fat, and protein intake on measures of insulin sensitivity: results from the OmniHeart trial. Diabetes Care. May 2013;36(5):1132-7. doi:10.2337/dc12-0869 | Intervention/Exposure
686 | Gadgil, MD, Kanaya, AM, Sands, C, et al. Diet Patterns Are Associated with Circulating Metabolites and Lipid Profiles of South Asians in the United States. J Nutr. Nov 2022;152(11):2358-2366. doi:10.1093/jn/nxac191 | Intervention/Exposure; Outcome
687 | Gadgil, MD, Krauss, RM. Changes in Insulin Resistance by Protein Source and Level of Saturated Fat-An Analysis of the Animal and Plant Protein and Cardiovascular Health (APPROACH) Trial. Diabetes. Jun 2023;72doi:10.2337/db23-603-P | Study design; Publication status
688 | Gadowski, AM, Nanayakkara, N, Heritier, S, et al. Association between Dietary Intake and Lipid-Lowering Therapy: Prospective Analysis of Data from Australian Diabetes, Obesity, and Lifestyle Study (AusDiab) Using a Quantile Regression Approach. Nutrients. Aug 9 2019;11(8)doi:10.3390/nu11081858 | Intervention/Exposure; Outcome
689 | Gaeini, Z, Mirmiran, P, Bahadoran, Z, et al. The association between dietary fats and the incidence risk of cardiovascular outcomes: Tehran Lipid and Glucose Study. Nutr Metab (Lond). 2021. 18:96. doi:10.1186/s12986-021-00624-6 | Intervention/Exposure
690 | Gagliardi, AC, Maranhão, RC, de Sousa, HP, et al. Effects of margarines and butter consumption on lipid profiles, inflammation markers and lipid transfer to HDL particles in free-living subjects with the metabolic syndrome. Eur J Clin Nutr. 2010. 64:1141-9. doi:10.1038/ejcn.2010.122 | Sample size/Power
691 | Galvão Cândido, F, Xavier Valente, F, da Silva, LE, et al. Consumption of extra virgin olive oil improves body composition and blood pressure in women with excess body fat: a randomized, double-blinded, placebo-controlled clinical trial. European Journal of Nutrition. 2018. 57:2445-2455. doi:10.1007/s00394-017-1517-9 | Intervention/Exposure
692 | Gao, JW, Hao, QY, Zhang, HF, et al. Low-Carbohydrate Diet Score and Coronary Artery Calcium Progression: Results From the CARDIA Study. Arterioscler Thromb Vasc Biol. Jan 2021;41(1):491-500. doi:10.1161/ATVBAHA.120.314838 | Intervention/Exposure
693 | Gao, M, Jebb, SA, Aveyard, P, et al. Associations between dietary patterns and the incidence of total and fatal cardiovascular disease and all-cause mortality in 116,806 individuals from the UK Biobank: a prospective cohort study. BMC Med. 2021. 19:83. doi:10.1186/s12916-021-01958-x | Intervention/Exposure
694 | Gao, X, Tian, Z, Zhao, D, et al. Associations between Adherence to Four A Priori Dietary Indexes and Cardiometabolic Risk Factors among Hyperlipidemic Patients. Nutrients. Jul 2021;13(7)doi:ARTN 2179 10.3390/nu13072179 | Study design; Intervention/Exposure
695 | Garaulet, M, Marín, C, Pérez-Llamas, F, et al. Adiposity and dietary intake in cardiovascular risk in an obese population from a Mediterranean area. Journal of Physiology and Biochemistry. 2004. 60:39-49. doi:10.1007/bf03168219 | Intervention/Exposure
696 | Garcia, PA, Hanson, KB, Kies, C, et al. Studies of women eating diets with different fatty acid composition. I. Plasma lipoproteins and steroid excretion. J Am Coll Nutr. Aug 1991;10(4):315-21. doi:10.1080/07315724.1991.10718158 | Intervention/Exposure
697 | García-Arias MT, Vaquero MP, García-Linares MC, et al. Lipoprotein profile in elderly persons from northwestern Spain consuming the Atlantic diet, a variant of the Mediterranean diet. Nutrition Research. 2003;23(12):1607-1618. doi:10.1016/j.nutres.2003.07.001 | Study design; Intervention/Exposure
698 | Garcia-Yu, IA, Garcia-Ortiz, L, Gomez-Marcos, MA, et al. Effects of Cocoa-Rich Chocolate on Blood Pressure, Cardiovascular Risk Factors, and Arterial Stiffness in Postmenopausal Women: A Randomized Clinical Trial. Nutrients. Jun 12 2020;12(6)doi:10.3390/nu12061758 | Comparator
699 | Gardner, CD, Coulston, A, Chatterjee, L, et al. The effect of a plant-based diet on plasma lipids in hypercholesterolemic adults: a randomized trial. Ann Intern Med. May 3 2005;142(9):725-33. doi:10.7326/0003-4819-142-9-200505030-00007 | Intervention/Exposure
700 | Gardner, CD, Messina, M, Kiazand, A, et al. Effect of two types of soy milk and dairy milk on plasma lipids in hypercholesterolemic adults: a randomized trial. J Am Coll Nutr. Dec 2007;26(6):669-77. doi:10.1080/07315724.2007.10719646 | Sample size/Power
701 | Gardner, CD, Newell, KA, Cherin, R, et al. The effect of soy protein with or without isoflavones relative to milk protein on plasma lipids in hypercholesterolemic postmenopausal women. American Journal of Clinical Nutrition. Apr 2001;73(4):728-735. | Intervention/Exposure
702 | Garousi, N, Tamizifar, B, Pourmasoumi, M, et al. Effects of lacto-ovo-vegetarian diet vs. standard-weight-loss diet on obese and overweight adults with non-alcoholic fatty liver disease: a randomised clinical trial. Arch Physiol Biochem. Dec 2023;129(4):975-983. doi:10.1080/13813455.2021.1890128 | Intervention/Exposure; Health status
703 | Gascon, A, Jacques, H, Moorjani, S, et al. Plasma lipoprotein profile and lipolytic activities in response to the substitution of lean white fish for other animal protein sources in premenopausal women. Am J Clin Nutr. Mar 1996;63(3):315-21. doi:10.1093/ajcn/63.3.315 | Sample size/Power
704 | Gaullier JM, Halse J, Høye K, et al. Conjugated linoleic acid supplementation for 1 y reduces body fat mass in healthy overweight humans. Am J Clin Nutr. 2004;79(6):1118-1125. doi:10.1093/ajcn/79.6.1118 | Intervention/Exposure
705 | Ge, S, Zha, L, Sobue, T, et al. Associations between dairy intake and mortality due to all-cause and cardiovascular disease: the Japan Public Health Center-based prospective study. Eur J Nutr. 2023. 62:2087-2104. doi:10.1007/s00394-023-03116-w | Comparator
706 | Geach, T. Heart failure: Processed meat and heart failure. Nat Rev Cardiol. Aug 2014;11(8):434. doi:10.1038/nrcardio.2014.93 | Study design; Publication status
707 | Gebauer, SK, Tracy, RP, Baer, DJ. Impact of stearic acid and oleic acid on hemostatic factors in the context of controlled diets consumed by healthy men. Eur J Clin Nutr. 2014. 68:1072-4. doi:10.1038/ejcn.2014.62 | Intervention/Exposure
708 | Geil, PB, Anderson, JW, Gustafson, NJ. Women and men with hypercholesterolemia respond similarly to an American Heart Association step 1 diet. J Am Diet Assoc. 1995. 95:436-41. doi:10.1016/s0002-8223(95)00118-2 | Intervention/Exposure
709 | Genoni, A, Lyons-Wall, P, Lo, J, et al. Cardiovascular, Metabolic Effects and Dietary Composition of Ad-Libitum Paleolithic vs. Australian Guide to Healthy Eating Diets: A 4-Week Randomised Trial. Nutrients. May 23 2016;8(5)doi:10.3390/nu8050314 | Intervention/Exposure
710 | Georgiopoulos, G, Karatzi, K, Euthimiou, E, et al. Association of macronutrient consumption with arterial aging in adults without clinically overt cardiovascular disease: a 5-year prospective cohort study. European Journal of Nutrition. Sep 2019;58(6):2305-2314. doi:10.1007/s00394-018-1781-3 | Intervention/Exposure
711 | Gerhard, GT, Connor, SL, Wander, RC, et al. Plasma lipid and lipoprotein responsiveness to dietary fat and cholesterol in premenopausal African American and white women. Am J Clin Nutr. Jul 2000;72(1):56-63. doi:10.1093/ajcn/72.1.56 | Intervention/Exposure; Sample size/Power
712 | Ghadirian, P, Shatenstein, B, Verdy, M, et al. The influence of dairy products on plasma uric acid in women. Eur J Epidemiol. Jun 1995;11(3):275-81. doi:10.1007/BF01719431 | Intervention/Exposure; Comparator
713 | Ghafoorunissa, , Reddy, V, Sesikaran, B. Palmolein and groundnut oil have comparable effects on blood lipids and platelet aggregation in healthy Indian subjects. Lipids. 1995. 30:1163-9. doi:10.1007/bf02536619 | Country
714 | Ghanavati, M, Hosseinabadi, SM, Parsa, SA, et al. Effect of a nut-enriched low-calorie diet on body weight and selected markers of inflammation in overweight and obese stable coronary artery disease patients: a randomized controlled study. European Journal of Clinical Nutrition. 2021. 75:1099-1108. doi:10.1038/s41430-020-00819-9 | Intervention/Exposure; Health status; Comparator
715 | Gharagozlian, S, Hansen, R, Haugen, M, et al. Changes in dietary pattern when including 700 g of salmon per week to patients with atherosclerotic heart disease. Clinical nutrition ESPEN. 2017. 19:38-44. doi:10.1016/j.clnesp.2017.02.004 | Health status
716 | Ghayour-Mobarhan, M, Sahebkar, A, Vakili, R, et al. Investigation of the effect of high dairy diet on body mass index and body fat in overweight and obese children. Indian J Pediatr. 2009. 76:1145-50. doi:10.1007/s12098-009-0231-x | Intervention/Exposure; Comparator
717 | Ghizi AC, de Almeida Silva M, Moraes FD, da Silva CL, Endringer DC, Scherer R, Lenz D, de Lima EM, Brasil GA, Maia JF, Bissoli NS, & de Andrade TU. Kefir improves blood parameters and reduces cardiovascular risks in patients with metabolic syndrome. PharmaNutrition. 2021. 16:100266. | Intervention/Exposure
718 | Ghosh, S, He, W, Gao, J, et al. Whole milk consumption is associated with lower risk of coronary artery calcification progression: evidences from the Multi-Ethnic Study of Atherosclerosis. European Journal of Nutrition. Mar 2021;60(2):1049-1058. doi:10.1007/s00394-020-02301-5 | Outcome
719 | Giacopini de Z MI, Alonso HV, Sánchez J, et al. Modificaciones de las lipoproteínas del plasma en voluntarios sometidos a dietas preparadas con aceite de girasol solo o mezclado con oleina de palma [Changes in the content of plasma lipoproteins in persons subjected to diets prepared with sunflower oil alone or mixed with palm olein]. Invest Clin. 2013;54(2):171-179. | Publication language
720 | Giezenaar, C, Lange, K, Hausken, T, et al. Acute effects of substitution, and addition, of carbohydrates and fat to protein on gastric emptying, blood glucose, gut hormones, appetite, and energy intake. Nutrients. 2018. 10:1451. doi:10.3390/nu10101451 | Intervention/Exposure; Duration
721 | Gigleux, I, Jenkins, DJ, Kendall, CW, et al. Comparison of a dietary portfolio diet of cholesterol-lowering foods and a statin on LDL particle size phenotype in hypercholesterolaemic participants. Br J Nutr. Dec 2007;98(6):1229-36. doi:10.1017/S0007114507781461 | Intervention/Exposure
722 | Gill, JM, Brown, JC, Caslake, MJ, et al. Effects of dietary monounsaturated fatty acids on lipoprotein concentrations, compositions, and subfraction distributions and on VLDL apolipoprotein B kinetics: dose-dependent effects on LDL. Am J Clin Nutr. Jul 2003;78(1):47-56. doi:10.1093/ajcn/78.1.47 | Intervention/Exposure
723 | Gillman, MW, Cupples, LA, Millen, BE, et al. Inverse association of dietary fat with development of ischemic stroke in men. JAMA. Dec 24-31 1997;278(24):2145-50. | Intervention/Exposure
724 | Gilmore, LA, Crouse, SF, Carbuhn, A, et al. Exercise attenuates the increase in plasma monounsaturated fatty acids and high-density lipoprotein cholesterol but not high-density lipoprotein 2b cholesterol caused by high-oleic ground beef in women. Nutr Res. 2013. 33:1003-11. doi:10.1016/j.nutres.2013.09.003 | Intervention/Exposure
725 | Gilmore, LA, Walzem, RL, Crouse, SF, et al. Consumption of high-oleic acid ground beef increases HDL-cholesterol concentration but both high- and low-oleic acid ground beef decrease HDL particle diameter in normocholesterolemic men. J Nutr. 2011. 141:1188-94. doi:10.3945/jn.110.136085 | Sample size/Power
726 | Ginsberg, HN, Barr, SL, Gilbert, A, et al. Reduction of plasma cholesterol levels in normal men on an American Heart Association Step 1 diet or a Step 1 diet with added monounsaturated fat. N Engl J Med. Mar 1 1990;322(9):574-9. doi:10.1056/NEJM199003013220902 | Intervention/Exposure
727 | Ginsberg, HN, Karmally, W, Siddiqui, M, et al. A dose-response study of the effects of dietary cholesterol on fasting and postprandial lipid and lipoprotein metabolism in healthy young men. Arterioscler Thromb. 1994. 14:576-86. doi:10.1161/01.atv.14.4.576 | Duration; Sample size/Power
728 | Ginsberg, HN, Karmally, W, Siddiqui, M, et al. Increases in dietary cholesterol are associated with modest increases in both LDL and HDL cholesterol in healthy young women. Arteriosclerosis, Thrombosis, and Vascular Biology. 1995. 15:169-178. doi:10.1161/01.ATV.15.2.169 | Sample size/Power
729 | Ginsberg, HN, Kris-Etherton, P, Dennis, B, et al. Effects of reducing dietary saturated fatty acids on plasma lipids and lipoproteins in healthy subjects: the DELTA Study, protocol 1. Arterioscler Thromb Vasc Biol. Mar 1998;18(3):441-9. doi:10.1161/01.atv.18.3.441 | Intervention/Exposure
730 | Giordano, G, Guarini, P, Ferrari, P, et al. Beneficial impact on cardiovascular risk profile of water buffalo meat consumption. Eur J Clin Nutr. 2010. 64:1000-6. doi:10.1038/ejcn.2010.108 | Study design
731 | Gleason, JA, Bourdet, KL, Koehn, K, et al. Cardiovascular risk reduction and dietary compliance with a home-delivered diet and lifestyle modification program. J Am Diet Assoc. Oct 2002;102(10):1445-51. doi:10.1016/s0002-8223(02)90320-2 | Intervention/Exposure; Health status; Comparator
732 | Glenn AJ, Guasch-Ferré M, Malik VS, et al. Portfolio Diet Score and Risk of Cardiovascular Disease: Findings From 3 Prospective Cohort Studies. Circulation. 2023;148(22):1750-1763. doi:10.1161/CIRCULATIONAHA.123.065551 | Intervention/Exposure
733 | Goff DC Jr, Shekelle RB, Katan MB, Gotto AM Jr, Stamler J. Does body fatness modify the association between dietary cholesterol and risk of coronary death? Results from the Chicago Western Electric Study. Arterioscler Thromb. 1992;12(7):755-761. doi:10.1161/01.atv.12.7.755 | Intervention/Exposure
734 | Gold, K, Wong, N, Tong, A, et al. Serum apolipoprotein and lipid profile effects of an oat-bran-supplemented, low-fat diet in children with elevated serum cholesterol. Ann N Y Acad Sci. 1991;623:429-31. doi:10.1111/j.1749-6632.1991.tb43758.x | Publication status; Sample size/Power
735 | Goldberg RB, Temprosa M, Mele L, et al. Change in adiponectin explains most of the change in HDL particles induced by lifestyle intervention but not metformin treatment in the Diabetes Prevention Program [published correction appears in Metabolism. 2017 Mar;68:184-186. doi: 10.1016/j.metabol.2016.11.007]. Metabolism. 2016;65(5):764-775. doi:10.1016/j.metabol.2015.11.011 | Intervention/Exposure
736 | Goldberg, RJ, Ellison, RC, Hosmer, DW, et al. Effects of alterations in fatty acid intake on the blood pressure of adolescents: the Exeter-Andover Project. Am J Clin Nutr. Jul 1992;56(1):71-6. doi:10.1093/ajcn/56.1.71 | Intervention/Exposure
737 | Goldbohm, RA, Chorus, AM, Galindo Garre, F, et al. Dairy consumption and 10-y total and cardiovascular mortality: a prospective cohort study in the Netherlands. Am J Clin Nutr. 2011. 93:615-27. doi:10.3945/ajcn.110.000430 | Comparator
738 | Golzarand, M, Bahadoran, Z, Mirmiran, P, et al. Protein Foods Group and 3-Year Incidence of Hypertension: A Prospective Study From Tehran Lipid and Glucose Study. J Ren Nutr. Jul 2016;26(4):219-25. doi:10.1053/j.jrn.2016.01.017 | Comparator
739 | Gonçalves S, Maria AV, Silva-Herdade AS, et al. Milk enriched with phytosterols reduces plasma cholesterol levels in healthy and hypercholesterolemic subjects. Nutrition Research. 2007;27(4):200-205. doi:10.1016/j.nutres.2007.03.003 | Comparator
740 | Gonciulea AR, Sellmeyer DE. The effect of dietary protein source on serum lipids: Secondary data analysis from a randomized clinical trial. J Clin Lipidol. 2017;11(1):46-54. doi:10.1016/j.jacl.2016.09.014 | Intervention/Exposure
741 | Gonzalez-Soto, M, Abdelmagid, SA, Ma, DWL, et al. Soy Consumption, but Not Dairy Consumption, Is Inversely Associated with Fatty Acid Desaturase Activity in Young Adults. Nutrients. Aug 17 2021;13(8)doi:10.3390/nu13082817 | Study design
742 | Goodrow, EF, Wilson, TA, Houde, SC, et al. Consumption of one egg per day increases serum lutein and zeaxanthin concentrations in older adults without altering serum lipid and lipoprotein cholesterol concentrations. J Nutr. 2006. 136:2519-24. doi:10.1093/jn/136.10.2519 | Intervention/Exposure
743 | Gopinath, B, Flood, VM, Burlutsky, G, et al. Dairy food consumption, blood pressure and retinal microcirculation in adolescents. Nutr Metab Cardiovasc Dis. Nov 2014;24(11):1221-7. doi:10.1016/j.numecd.2014.05.014 | Intervention/Exposure; Comparator
744 | Gopinath, B, Flood, VM, Wang, JJ, et al. Lower dairy products and calcium intake is associated with adverse retinal vascular changes in older adults. Nutrition Metabolism and Cardiovascular Diseases. Feb 2014;24(2):155-161. doi:10.1016/j.numecd.2013.06.009 | Outcome
745 | Gopinath, B, Flood, VM, Burlutksy, G, et al. Consumption of nuts and risk of total and cause-specific mortality over 15 years. Nutr Metab Cardiovasc Dis. Dec 2015;25(12):1125-31. doi:10.1016/j.numecd.2015.09.006 | Intervention/Exposure
746 | Gorder, DD, Bartsch, GE, Tillotson, JL, et al. Food group and macronutrient intakes, trial years 1-6, in the special intervention and usual care groups in the Multiple Risk Factor Intervention Trial. Am J Clin Nutr. Jan 1997;65(1 Suppl):258S-271S. doi:10.1093/ajcn/65.1.258S | Intervention/Exposure; Outcome
747 | Goulet, J, Lamarche, B, Nadeau, G, et al. Effect of a nutritional intervention promoting the Mediterranean food pattern on plasma lipids, lipoproteins and body weight in healthy French-Canadian women. Atherosclerosis. 2003. 170:115-24. doi:10.1016/s0021-9150(03)00243-0 | Intervention/Exposure
748 | Gramenzi, A, Gentile, A, Fasoli, M, et al. Association between Certain Foods and Risk of Acute Myocardial-Infarction in Women. Bmj-British Medical Journal. Mar 24 1990;300(6727):771-773. doi:DOI 10.1136/bmj.300.6727.771 | Study design
749 | Grant, WB. Milk and other dietary influences on coronary heart disease. Altern Med Rev. Aug 1998;3(4):281-94. | Study design
750 | Grau, N, Mohammadifard, N, Hassannejhad, R, et al. Red and processed meat consumption and risk of incident cardiovascular disease and mortality: Isfahan cohort study. Int J Food Sci Nutr. Jun 2022;73(4):503-512. doi:10.1080/09637486.2021.1993797 | Comparator
751 | Greco, A, Brugnera, A, Adorni, R, et al. Protein Intake and Physical Activity in Newly Diagnosed Patients with Acute Coronary Syndrome: A 5-Year Longitudinal Study. Nutrients. Feb 16 2021;13(2)doi:10.3390/nu13020634 | Health status
752 | Green, P, Fuchs, J, Schoenfeld, N, et al. Effects of fish-oil ingestion on cardiovascular risk factors in hyperlipidemic subjects in Israel: a randomized, double-blind crossover study. Am J Clin Nutr. Dec 1990;52(6):1118-24. doi:10.1093/ajcn/52.6.1118 | Intervention/Exposure; Sample size/Power
753 | Greenberg, JA, Manson, JE, Neuhouser, ML, et al. Chocolate intake and heart disease and stroke in the Women’s Health Initiative: a prospective analysis. Am J Clin Nutr. 2018. 108:41-48. doi:10.1093/ajcn/nqy073 | Comparator
754 | Gribbin, S, Enticott, J, Hodge, AM, et al. Association of carbohydrate and saturated fat intake with cardiovascular disease and mortality in Australian women. Heart. May 25 2022;108(12):932-939. doi:10.1136/heartjnl-2021-319654 | Intervention/Exposure
755 | Griffin, BA, Lovegrove, JA. Butter Increases High-Density Lipoprotein Functional Capacity: Is This Compensation for Its Adverse Effect on Serum Low-Density Lipoprotein Cholesterol?. Journal of Nutrition. 2018. 148:1069-1070. doi:10.1093/jn/nxy086 | Study design; Publication status
756 | Grimaldi, M, Ciano, O, Manzo, M, et al. Intensive dietary intervention promoting the Mediterranean diet in people with high cardiometabolic risk: a non-randomized study. Acta Diabetol. 2018. 55:219-226. doi:10.1007/s00592-017-1078-7 | Intervention/Exposure
757 | Grzybek A, Stolarska I, Klosiewicz-Latoszek L. Hypolipemic diet introduced on the outpatient basis: The effects on lipid and lipoprotein serum levels. Kardiologia Polska. 2001;55(12):530-535. | Intervention/Exposure
758 | Gu, X, Drouin-Chartier, J-P, Sacks, FM, et al. Red meat intake and risk of type 2 diabetes in a prospective cohort study of United States females and males. Am J Clin Nutr. Dec 2023;118(6):1153-1163. doi:10.1016/j.ajcnut.2023.08.021 | Outcome
759 | Guallar-Castillón, P, Rodríguez-Artalejo, F, Tormo, MJ, et al. Major dietary patterns and risk of coronary heart disease in middle-aged persons from a Mediterranean country: the EPIC-Spain cohort study. Nutr Metab Cardiovasc Dis. 2012. 22:192-9. doi:10.1016/j.numecd.2010.06.004 | Intervention/Exposure
760 | Guarneiri, LL, Paton, CM, Cooper, JA. Pecan-enriched diets decrease postprandial lipid peroxidation and increase total antioxidant capacity in adults at-risk for cardiovascular disease. Nutr Res. 2021. 93:69-78. doi:10.1016/j.nutres.2021.07.004 | Duration; Sample size/Power
761 | Guasch-Ferré, M, Babio, N, Martínez-González, MA, et al. Dietary fat intake and risk of cardiovascular disease and all-cause mortality in a population at high risk of cardiovascular disease. American journal of clinical nutrition. 2015. 102:1563-1573. doi:10.3945/ajcn.115.116046 | Comparator
762 | Guasch-Ferré, M, Hruby, A, Salas-Salvadó, J, et al. Olive oil consumption and risk of type 2 diabetes in US women. Am J Clin Nutr. 2015. 102:479-86. doi:10.3945/ajcn.115.112029 | Outcome
763 | Guess, N, Wijesuriya, M, Vasantharajah, L, et al. The effect of dietary changes on distinct components of the metabolic syndrome in a young Sri Lankan population at high risk of CVD. British Journal of Nutrition. Aug 28 2016;116(4):719-727. doi:10.1017/S0007114516002476 | Comparator
764 | Guevara-Cruz, M, Flores-López, AG, Aguilar-López, M, et al. Improvement of Lipoprotein Profile and Metabolic Endotoxemia by a Lifestyle Intervention That Modifies the Gut Microbiota in Subjects With Metabolic Syndrome. J Am Heart Assoc. 2019. 8:e012401. doi:10.1161/jaha.119.012401 | Intervention/Exposure
765 | Guevara-Cruz, M, Medina-Vera, I, Flores-López, A, et al. Development of a Genetic Score to Predict an Increase in HDL Cholesterol Concentration After a Dietary Intervention in Adults with Metabolic Syndrome. J Nutr. Jul 1 2019;149(7):1116-1121. doi:10.1093/jn/nxz060 | Intervention/Exposure
766 | Guinard, JX, Sechevich, PJ, Meaker, K, et al. Sensory responses to fat are not affected by varying dietary energy intake from fat and saturated fat over ranges common in the American diet. J Am Diet Assoc. Jun 1999;99(6):690-6. doi:10.1016/S0002-8223(99)00167-4 | Intervention/Exposure; Sample size/Power
767 | Gulseth, HL, Gjelstad, IM, Tierney, AC, et al. Dietary fat modifications and blood pressure in subjects with the metabolic syndrome in the LIPGENE dietary intervention study. Br J Nutr. Jul 2010;104(2):160-3. doi:10.1017/S0007114510000565 | Intervention/Exposure
768 | Gulseth, HL, Gjelstad, IMF, Tiereny, AC, et al. Effects of dietary fat on insulin secretion in subjects with the metabolic syndrome. Eur J Endocrinol. May 1 2019;180(5):321-328. doi:10.1530/EJE-19-0022 | Intervention/Exposure
769 | Guo, J, Dougkas, A, Elwood, PC, et al. Dairy Foods and Body Mass Index over 10-Year: Evidence from the Caerphilly Prospective Cohort Study. Nutrients. Oct 16 2018;10(10)doi:10.3390/nu10101515 | Outcome
770 | Guo, J, Givens, DI, Heitmann, BL. Association between dairy consumption and cardiovascular disease events, bone fracture and all-cause mortality. PLoS One. 2022. 17:e0271168. doi:10.1371/journal.pone.0271168 | Comparator
771 | Guo, J, Li, W, Wang, Y, et al. Influence of dietary patterns on the risk of acute myocardial infarction in China population: the INTERHEART China study. Chin Med J (Engl). Feb 2013;126(3):464-70. | Study design
772 | Guo, X, Xu, Y, He, H, et al. Effects of a Meal Replacement on Body Composition and Metabolic Parameters among Subjects with Overweight or Obesity. Journal of obesity. 2018. 2018:2837367. doi:10.1155/2018/2837367 | Intervention/Exposure
773 | Gurdeniz, G, Uusitupa, M, Hermansen, K, et al. Analysis of the SYSDIET Healthy Nordic Diet randomized trial based on metabolic profiling reveal beneficial effects on glucose metabolism and blood lipids. Clin Nutr. Feb 2022;41(2):441-451. doi:10.1016/j.clnu.2021.12.031 | Intervention/Exposure
774 | Gustafsson, IB, Öhrvall, M, Ekstrand, B, et al. Moderate amounts of n-3 fatty acid enriched seafood products are effective in lowering serum triglycerides and blood pressure in healthy subjects. Journal of Human Nutrition and Dietetics. Apr 1996;9(2):135-145. doi:DOI 10.1046/j.1365-277X.1996.00447.x | Sample size/Power
775 | Gustafsson, IB, Vessby, B, Ohrvall, M, et al. A diet rich in monounsaturated rapeseed oil reduces the lipoprotein cholesterol concentration and increases the relative content of n-3 fatty acids in serum in hyperlipidemic subjects. Am J Clin Nutr. Mar 1994;59(3):667-74. doi:10.1093/ajcn/59.3.667 | Duration
776 | Gwynne, M, Mounsey, A. Mediterranean diet: higher fat but lower risk. Article. J Fam Pract. Dec 2013;62(12):745-8. | Study design
777 | Gylling, H, Halonen, J, Lindholm, H, et al. The effects of plant stanol ester consumption on arterial stiffness and endothelial function in adults: a randomised controlled clinical trial. BMC Cardiovasc Disord. 2013. 13:50. doi:10.1186/1471-2261-13-50 | Intervention/Exposure; Comparator
778 | Gylling, H, Miettinen, TA. Baseline intestinal absorption and synthesis of cholesterol regulate its response to hypolipidaemic treatments in coronary patients. Atherosclerosis. 2002. 160:477-81. doi:10.1016/s0021-9150(01)00608-6 | Health status; Sample size/Power
779 | Gylling, H, Miettinen, TA. Cholesterol reduction by different plant stanol mixtures and with variable fat intake. Metabolism. 1999. 48:575-80. doi:10.1016/s00260495(99)90053-7 | Sample size/Power
780 | H Arghavani, S O’Connor, C Fortier, I Rudkowska. Lack of change in blood pressure and arterial stiffness after high dairy intake in hyperinsulinemic subjects: a cross-over randomized controlled trial. Appl Physiol Nutr Metab. Mar 1 2024;49(3):350-359. doi:10.1139/apnm-2023-0053 | Sample size/Power
781 | Ha AW, Kim WK, Kim SH. Cow’s Milk Intake and Risk of Coronary Heart Disease in Korean Postmenopausal Women. Nutrients. 2022;14(5):1092. Published 2022 Mar 5. doi:10.3390/nu14051092 | Study design
782 | Haber, SL, Gallus, K. Effects of dark chocolate on blood pressure in patients with hypertension. Am J Health Syst Pharm. Aug 1 2012;69(15):1287-8, 1290, 1292-3. doi:10.2146/ajhp110498 | Study design
783 | Hageman, PA, Pullen, CH, Hertzog, M, et al. Effectiveness of tailored lifestyle interventions, using web-based and print-mail, for reducing blood pressure among rural women with prehypertension: main results of the Wellness for Women: DASHing towards Health clinical trial. Int J Behav Nutr Phys Act. 2014. 11:148. doi:10.1186/s12966-014-0148-2 | Intervention/Exposure
784 | Hagen, IV, Helland, A, Bratlie, M, et al. High intake of fatty fish, but not of lean fish, affects serum concentrations of TAG and HDL-cholesterol in healthy, normal-weight adults: a randomised trial. Br J Nutr. 2016. 116:648-57. doi:10.1017/s0007114516002555 | Intervention/Exposure; Sample size/Power
785 | Haji-Ghazi Tehrani, L, Mousavi, SN, Chiti, H, et al. Effect of Atkins versus a low-fat diet on gut microbiota, and cardiometabolic markers in obese women following an energy-restricted diet: Randomized, crossover trial. Nutrition, Metabolism and Cardiovascular Diseases. 2022. 32:1734-1741. doi:10.1016/j.numecd.2022.04.007 | Intervention/Exposure
786 | Hajihashemi, P, Hassannejad, R, Haghighatdoost, F, et al. The long-term association of different dietary protein sources with metabolic syndrome. Scientific reports. 2021. 11:19394. doi:10.1038/s41598-021-98688-0 | Outcome
787 | Hajiluian, G, Abbasalizad Farhangi, M, Jahangiry, L. Mediterranean dietary pattern and VEGF +405 G/C gene polymorphisms in patients with metabolic syndrome: An aspect of gene-nutrient interaction. PLoS One. 2017. 12:e0171637. doi:10.1371/journal.pone.0171637 | Study design
788 | Hajipoor, S, Hekmatdoost, A, Rezaei, M, et al. The effect of yogurt co-fortified with probiotic and vitamin D on lipid profile, anthropometric indices and serum 25-hydroxi vitamin D in obese adult: A Double-Blind Randomized- Controlled Trial. Food Sci Nutr. 2021. 9:303-312. doi:10.1002/fsn3.1996 | Intervention/Exposure; Sample size/Power
789 | Haldar, S, Wong, LH, Tay, SL, et al. Two Blends of Refined Rice Bran, Flaxseed, and Sesame Seed Oils Affect the Blood Lipid Profile of Chinese Adults with Borderline Hypercholesterolemia to a Similar Extent as Refined Olive Oil. J Nutr. 2020. 150:3141-3151. doi:10.1093/jn/nxaa274 | Intervention/Exposure
790 | Hall, WD, Feng, Z, George, VA, et al. Low-fat diet: effect on anthropometrics, blood pressure, glucose, and insulin in older women. Ethn Dis. Summer 2003;13(3):337-43. | Intervention/Exposure
791 | Hallikainen, M, Sarkkinen, E, Wester, I, et al. Short-term LDL cholesterol-lowering efficacy of plant stanol esters. BMC Cardiovasc Disord. 2002. 2:14. doi:10.1186/1471-2261-2-14 | Duration
792 | Hallikainen, MA, Sarkkinen, ES, Gylling, H, et al. Comparison of the effects of plant sterol ester and plant stanol ester-enriched margarines in lowering serum cholesterol concentrations in hypercholesterolaemic subjects on a low-fat diet. Eur J Clin Nutr. 2000. 54:715-25. doi:10.1038/sj.ejcn.1601083 | Comparator
793 | Hallikainen, MA, Sarkkinen, ES, Uusitupa, MI. Effects of low-fat stanol ester enriched margarines on concentrations of serum carotenoids in subjects with elevated serum cholesterol concentrations. Eur J Clin Nutr. 1999. 53:966-9. doi:10.1038/sj.ejcn.1600882 | Intervention/Exposure; Outcome; Comparator
794 | Hallikainen, MA, Uusitupa, MI. Effects of low-fat stanol ester enriched margarines on concentrations of serum carotenoids in subjects with elevated serum cholesterol concentrations. Eur J Clin Nutr. Dec 1999;53(12):966-9. doi:10.1038/sj.ejcn.1600882 | Intervention/Exposure; Sample size/Power
795 | Halton, TL, Willett, WC, Liu, S, et al. Low-carbohydrate-diet score and the risk of coronary heart disease in women. N Engl J Med. Nov 9 2006;355(19):1991-2002. doi:10.1056/NEJMoa055317 | Intervention/Exposure
796 | Halvorsen, B, Almendingen, K, Nenseter, MS, et al. Effects of partially hydrogenated fish oil, partially hydrogenated soybean oil and butter on the susceptibility of low density lipoprotein to oxidative modification in men. Eur J Clin Nutr. Jun 1996;50(6):364-70. | Sample size/Power
797 | Hamer, M, Mishra, GD. Dietary patterns and cardiovascular risk markers in the UK Low Income Diet and Nutrition Survey. Nutr Metab Cardiovasc Dis. 2010. 20:491-7. doi:10.1016/j.numecd.2009.05.002 | Study design; Intervention/Exposure
798 | Hammoud, A, Gastaldi, M, Maillot, M, et al. APOB-516 T allele homozygous subjects are unresponsive to dietary changes in a three-month primary intervention study targeted to reduce fat intake. Genes Nutr. 2010. 5:29-37. doi:10.1007/s12263-009-0155-0 | Intervention/Exposure
799 | Han, SN, Leka, LS, Lichtenstein, AH, et al. Effect of hydrogenated and saturated, relative to polyunsaturated, fat on immune and inflammatory responses of adults with moderate hypercholesterolemia. J Lipid Res. Mar 2002;43(3):445-52. | Sample size/Power
800 | Hannon, BA, Edwards, CG, Thompson, SV, et al. Single Nucleotide Polymorphisms Related to Lipoprotein Metabolism Are Associated with Blood Lipid Changes following Regular Avocado Intake in a Randomized Control Trial among Adults with Overweight and Obesity. Journal of Nutrition. Jun 2020;150(6):1379-1387. doi:10.1093/jn/nxaa054 | Intervention/Exposure
801 | Hansel, B, Nicolle, C, Lalanne, F, et al. Effect of low-fat, fermented milk enriched with plant sterols on serum lipid profile and oxidative stress in moderate hypercholesterolemia. Am J Clin Nutr. 2007. 86:790-6. doi:10.1093/ajcn/86.3.790 | Comparator
802 | Hansen, JB, Berge, LN, Svensson, B, et al. Effects of cod liver oil on lipids and platelets in males and females. Eur J Clin Nutr. Feb 1993;47(2):123-31. | Intervention/Exposure
803 | Hansen-Krone, IJ, Enga, KF, Njølstad, I, et al. Heart healthy diet and risk of myocardial infarction and venous thromboembolism. The Tromso Study. Thromb Haemost. Sep 2012;108(3):554-60. doi:10.1160/TH11-11-0818 | Intervention/Exposure
804 | Hansson, P, Holven, KB, Øyri, LKL, et al. Meals with Similar Fat Content from Different Dairy Products Induce Different Postprandial Triglyceride Responses in Healthy Adults: A Randomized Controlled Cross-Over Trial. J Nutr. 2019. 149:422-431. doi:10.1093/jn/nxy291 | Duration; Sample size/Power
805 | Hara, H, Abbott, WG, Patti, L, et al. Increased receptor binding of low-density lipoprotein from individuals consuming a high-carbohydrate, low-saturated-fat diet. Metabolism. Nov 1992;41(11):1154-60. doi:10.1016/0026-0495(92)90002-r | Duration; Sample size/Power
806 | Hardy, DS, Racette, SB, Garvin, JT, et al. Ancestry specific associations of a genetic risk score, dietary patterns and metabolic syndrome: a longitudinal ARIC study. BMC Med Genomics. 2021. 14:118. doi:10.1186/s12920-021-00961-8 | Intervention/Exposure
807 | Hargrove, RL, Etherton, TD, Pearson, TA, et al. Low fat and high monounsaturated fat diets decrease human low density lipoprotein oxidative susceptibility in vitro. J Nutr. Jun 2001;131(6):1758-63. doi:10.1093/jn/131.6.1758 | Intervention/Exposure; Duration; Sample size/Power
808 | Hari, S, Ochiai, R, Shioya, Y, et al. Safety evaluation of the consumption of high dose milk fat globule membrane in healthy adults: a double-blind, randomized controlled trial with parallel group design. Bioscience, biotechnology, and biochemistry. 2015. 79:1172-1177. doi:10.1080/09168451.2015.1012150 | Intervention/Exposure; Sample size/Power
809 | Haring, B, Misialek, JR, Rebholz, CM, et al. Association of Dietary Protein Consumption With Incident Silent Cerebral Infarcts and Stroke: The Atherosclerosis Risk in Communities (ARIC) Study. Stroke. 2015. 46:3443-50. doi:10.1161/strokeaha.115.010693 | Comparator
810 | Haring, B, Wang, W, Fretts, A, et al. Red meat consumption and cardiovascular target organ damage (from the Strong Heart Study). J Hypertens. 2017. 35:1794-1800. doi:10.1097/hjh.0000000000001385 | Intervention/Exposure; Comparator
811 | Harman, NL, Leeds, AR, Griffin, BA. Increased dietary cholesterol does not increase plasma low density lipoprotein when accompanied by an energy-restricted diet and weight loss. Eur J Nutr. 2008. 47:287-93. doi:10.1007/s00394-008-0730-y | Intervention/Exposure
812 | Harnden, KE, Frayn, KN, Hodson, L. Dietary Approaches to Stop Hypertension (DASH) diet: applicability and acceptability to a UK population. J Hum Nutr Diet. Feb 2010;23(1):3-10. doi:10.1111/j.1365-277X.2009.01007.x | Intervention/Exposure
813 | Harris, C, Buyken, A, Koletzko, S, et al. Dietary Fatty Acids and Changes in Blood Lipids during Adolescence: The Role of Substituting Nutrient Intakes. Nutrients. Feb 11 2017;9(2)doi:10.3390/nu9020127 | Intervention/Exposure
814 | Harris, CP, von Berg, A, Berdel, D, et al. Association of Dietary Fatty Acids with Blood Lipids is Modified by Physical Activity in Adolescents: Results from the GINIplus and LISA Birth Cohort Studies. Nutrients. Sep 25 2018;10(10)doi:10.3390/nu10101372 | Intervention/Exposure; Population
815 | Harris, M, Hutchins, A, Fryda, L. The Impact of Virgin Coconut Oil and High-Oleic Safflower Oil on Body Composition, Lipids, and Inflammatory Markers in Postmenopausal Women. J Med Food. 2017. 20:345-351. doi:10.1089/jmf.2016.0114 | Sample size/Power
816 | Harris, WS, Connor, WE, Illingworth, DR, et al. Effects of fish oil on VLDL triglyceride kinetics in humans. J Lipid Res. Sep 1990;31(9):1549-58. | Duration; Sample size/Power
817 | Harriss, LR, English, DR, Powles, J, et al. Dietary patterns and cardiovascular mortality in the Melbourne Collaborative Cohort Study. Am J Clin Nutr. 2007. 86:221-9. doi:10.1093/ajcn/86.1.221 | Intervention/Exposure
818 | Harsha, DW, Lin, PH, Obarzanek, E, et al. Dietary Approaches to Stop Hypertension: a summary of study results. DASH Collaborative Research Group. J Am Diet Assoc. Aug 1999;99(8 Suppl):S35-9. doi:10.1016/s0002-8223(99)00414-9 | Intervention/Exposure
819 | Hartiala, O, Kajander, S, Knuuti, J, et al. Life-course risk factor levels and coronary artery calcification. The Cardiovascular Risk in Young Finns Study. Int J Cardiol. Dec 15 2016;225:23-29. doi:10.1016/j.ijcard.2016.09.080 | Intervention/Exposure
820 | Hartman, TJ, Himes, JH, McCarthy, PR, et al. Effects of a low-fat, worksite intervention on blood lipids and lipoproteins. J Occup Environ Med. Jun 1995;37(6):690-6. doi:10.1097/00043764-199506000-00010 | Study design; Intervention/Exposure
821 | Harvey, CJDC, Schofield, GM, Zinn, C, et al. Low-carbohydrate diets differing in carbohydrate restriction improve cardiometabolic and anthropometric markers in healthy adults: A randomised clinical trial. PeerJ. 2019;7:e6273. doi:10.7717/peerj.6273 | Intervention/Exposure; Sample size/Power
822 | Hassannejad, R, Moosavian, SP, Mohammadifard, N, et al. Long-term association of red meat consumption and lipid profile: A 13-year prospective population-based cohort study. Nutrition. 2021. 86:111144. doi:10.1016/j.nut.2021.111144 | Comparator
823 | Hassapidou, M, Tziomalos, K, Lazaridou, S, et al. The Nutrition Health Alliance (NutriHeAl) Study: A Randomized, Controlled, Nutritional Intervention Based on Mediterranean Diet in Greek Municipalities. J Am Coll Nutr. May-Jun 2020;39(4):338-344. doi:10.1080/07315724.2019.1660928 | Intervention/Exposure; Outcome
824 | Hata, Y, Yamamoto, M, Ohni, M, et al. A placebo-controlled study of the effect of sour milk on blood pressure in hypertensive subjects. Am J Clin Nutr. Nov 1996;64(5):767-71. doi:10.1093/ajcn/64.5.767 | Intervention/Exposure; Comparator
825 | Haub, MD, Wells, AM, Campbell, WW. Beef and soy-based food supplements differentially affect serum lipoprotein-lipid profiles because of changes in carbohydrate intake and novel nutrient intake ratios in older men who resistive-train. Metabolism. 2005. 54:769-74. doi:10.1016/j.metabol.2005.01.019 | Sample size/Power
826 | Haufe, S, Engeli, S, Kast, P, et al. Randomized comparison of reduced fat and reduced carbohydrate hypocaloric diets on intrahepatic fat in overweight and obese human subjects. Hepatology. May 2011;53(5):1504-14. doi:10.1002/hep.24242 | Intervention/Exposure
827 | Haufe, S, Utz, W, Engeli, S, et al. Left ventricular mass and function with reduced-fat or reduced-carbohydrate hypocaloric diets in overweight and obese subjects. Hypertension. Jan 2012;59(1):70-5. doi:10.1161/HYPERTENSIONAHA.111.178616 | Intervention/Exposure
828 | Hauhouot-Attoungbré, ML, Yayo, SE, Yao, C, et al. Consumption of dark chocolate reduced lipoprotein cardiovascular risk factors in an Ivorian population. Biochimica Clinica. 2011;35(3):190-192. | Country
829 | Hautaniemi, EJ, Tikkakoski, AJ, Tahvanainen, A, et al. Effect of fermented milk product containing lactotripeptides and plant sterol esters on haemodynamics in subjects with the metabolic syndrome-a randomised, double-blind, placebo-controlled study. British journal of nutrition. 2015. 114:376-386. doi:10.1017/S0007114515002032 | Intervention/Exposure; Comparator
830 | Hautero, U, Laakso, P, Linderborg, K, et al. Proportions and concentrations of serum n-3 fatty acids can be increased by dietary counseling during pregnancy. European Journal of Clinical Nutrition. Nov 2013;67(11):1163-1168. doi:10.1038/ejcn.2013.169 | Intervention/Exposure; Outcome
831 | Hayman, LL. The Dietary Intervention Study in Children (DISC): progress and prospects for primary prevention. Prog Cardiovasc Nurs. Winter 2003;18(1):4-5. doi:10.1111/j.0889-7204.2003.01781.x | Study design; Publication status
832 | He, D, Sun, N, Xiong, S, et al. Association between the proportions of carbohydrate and fat intake and hypertension risk: findings from the China Health and Nutrition Survey. Journal of Hypertension. Jul 2021;39(7):1386-1392. doi:10.1097/Hjh.0000000000002803 | Intervention/Exposure; Country
833 | He, DH, Yang, M, Zhang, RH, et al. Dietary Patterns Associated Metabolic Syndrome in Chinese Adults. Biomed Environ Sci. 2015. 28:370-3. doi:10.3967/bes2015.051 | Intervention/Exposure
834 | He, J, Wofford, MR, Reynolds, K, et al. Effect of dietary protein supplementation on blood pressure: a randomized, controlled trial. Circulation. 2011. 124:589-95. doi:10.1161/circulationaha.110.009159 | Intervention/Exposure
835 | He, K, Guo, L-L, Tang, H, et al. A Freshwater Fish-Based Diet Alleviates Liver Steatosis by Modulating Gut Microbiota and Metabolites: A Clinical Randomized Controlled Trial in Chinese Participants With Nonalcoholic Fatty Liver Disease. Article. Am J Gastroenterol. Oct 1 2022;117(10):1621-1631. doi:10.14309/ajg.0000000000001885 | Health status; Sample size/Power
836 | He, K, Merchant, A, Rimm, EB, et al. Dietary fat intake and risk of stroke in male US healthcare professionals: 14 year prospective cohort study. BMJ. Oct 4 2003;327(7418):777-82. doi:10.1136/bmj.327.7418.777 | Comparator
837 | He, M, Guo, Z, Lu, Z, et al. High milk consumption is associated with carotid atherosclerosis in middle and old-aged Chinese. Int J Cardiol Hypertens. 2020. 5:100031. doi:10.1016/j.ijchy.2020.100031 | Study design
838 | Heald, AH, Golding, C, Sharma, R, et al. A substitution model of dietary manipulation is an effective means of optimising lipid profile, reducing C-reactive protein and increasing insulin-like growth factor-1. British Journal of Nutrition. 2004. 92:809-818. doi:10.1079/BJN20041262 | Study design; Intervention/Exposure
839 | Hebert, JR, Ebbeling, CB, Ockene, IS, et al. A dietitian-delivered group nutrition program leads to reductions in dietary fat, serum cholesterol, and body weight: the Worcester Area Trial for Counseling in Hyperlipidemia (WATCH). J Am Diet Assoc. May 1999;99(5):544-52. doi:10.1016/s0002-8223(99)00136-4 | Intervention/Exposure
840 | Heianza, Y, Ma, W, DiDonato, JA, et al. Ten-year changes in plasma L-carnitine levels and risk of coronary heart disease. Eur J Nutr. Apr 2022;61(3):1353-1362. doi:10.1007/s00394-021-02713-x | Intervention/Exposure
841 | Heidemann, C, Scheidt-Nave, C, Richter, A, et al. Dietary patterns are associated with cardiometabolic risk factors in a representative study population of German adults. Br J Nutr. 2011. 106:1253-62. doi:10.1017/s0007114511001504 | Study design; Intervention/Exposure
842 | Heidemann, C, Schulze, MB, Franco, OH, et al. Dietary patterns and risk of mortality from cardiovascular disease, cancer, and all causes in a prospective cohort of women. Circulation. 2008. 118:230-7. doi:10.1161/circulationaha.108.771881 | Intervention/Exposure
843 | Heilbronn, LK, Noakes, M, Clifton, PM. Effect of energy restriction, weight loss, and diet composition on plasma lipids and glucose in patients with type 2 diabetes. Diabetes Care. 1999. 22:889-95. doi:10.2337/diacare.22.6.889 | Intervention/Exposure; Health status
844 | Heitmann, BL, Lissner, L. Can adverse effects of dietary fat intake be overestimated as a consequence of dietary fat underreporting?. Public Health Nutr. 2005. 8:1322-7. doi:10.1079/phn2005750 | Intervention/Exposure
845 | Helal, O, Berrougui, H, Loued, S, et al. Extra-virgin olive oil consumption improves the capacity of HDL to mediate cholesterol efflux and increases ABCA1 and ABCG1 expression in human macrophages. Br J Nutr. May 28 2013;109(10):1844-55. doi:10.1017/S0007114512003856 | Study design; Sample size/Power
846 | Hellénius, ML, de Faire, U, Berglund, B, et al. Diet and exercise are equally effective in reducing risk for cardiovascular disease. Results of a randomized controlled study in men with slightly to moderately raised cardiovascular risk factors. Atherosclerosis. 1993. 103:81-91. doi:10.1016/0021-9150(93)90042-s | Intervention/Exposure
847 | Heller, RF, Walker, RJ, Boyle, CA, et al. A randomised controlled trial of a dietary advice program for relatives of heart attack victims. Med J Aust. Nov 7 1994;161(9):529-31. doi:10.5694/j.1326-5377.1994.tb127595.x | Study design; Intervention/Exposure
848 | Hellstrand, S, Ericson, U, Schulz, CA, et al. Genetic susceptibility to dyslipidemia and incidence of cardiovascular disease depending on a diet quality index in the Malmö Diet and Cancer cohort. Genes Nutr. 2016. 11:20. doi:10.1186/s12263-016-0536-0 | Intervention/Exposure
849 | Hendriks, HF, Brink, EJ, Meijer, GW, et al. Safety of long-term consumption of plant sterol esters-enriched spread. Eur J Clin Nutr. 2003. 57:681-92. doi:10.1038/sj.ejcn.1601598 | Intervention/Exposure; Comparator
850 | Hendriksen, RB, van der Gaag, EJ. Effect of a dietary intervention including minimal and unprocessed foods, high in natural saturated fats, on the lipid profile of children, pooled evidence from randomized controlled trials and a cohort study. PLoS One. 2022. 17:e0261446. doi:10.1371/journal.pone.0261446 | Intervention/Exposure
851 | Henkin, Y, Garber, DW, Osterlund, LC, et al. Saturated fats, cholesterol, and dietary compliance. Arch Intern Med. Jun 1992;152(6):1167-74. | Intervention/Exposure
852 | Heraclides, A, Mishra, GD, Hardy, RJ, et al. Dairy intake, blood pressure and incident hypertension in a general British population: the 1946 birth cohort. Eur J Nutr. 2012. 51:583-91. doi:10.1007/s00394-011-0242-z | Intervention/Exposure; Comparator
853 | Herbel BK, McGuire MK, McGuire MA, Shultz TD. Safflower oil consumption does not increase plasma conjugated linoleic acid concentrations in humans. Am J Clin Nutr. 1998;67(2):332-337. doi:10.1093/ajcn/67.2.332 | Intervention/Exposure; Sample size/Power
854 | Hernáez Á, Castañer O, Elosua R, et al. Mediterranean Diet Improves High-Density Lipoprotein Function in High-Cardiovascular-Risk Individuals: A Randomized Controlled Trial. Circulation. 2017;135(7):633-643. doi:10.1161/CIRCULATIONAHA.116.023712 | Intervention/Exposure; Comparator
855 | Hernáez, Á, Castañer, O, Tresserra-Rimbau, A, et al. Mediterranean Diet and Atherothrombosis Biomarkers: A Randomized Controlled Trial. Mol Nutr Food Res. Oct 2020;64(20):e2000350. doi:10.1002/mnfr.202000350 | Intervention/Exposure
856 | Hernandez, TL, Sutherland, JP, Wolfe, P, et al. Lack of suppression of circulating free fatty acids and hypercholesterolemia during weight loss on a high-fat, lowcarbohydrate diet. Am J Clin Nutr. Mar 2010;91(3):578-85. doi:10.3945/ajcn.2009.27909 | Intervention/Exposure
857 | Hernández-Alonso P, Salas-Salvadó J, Ruiz-Canela M, et al. High dietary protein intake is associated with an increased body weight and total death risk. Clin Nutr. 2016;35(2):496-506. doi:10.1016/j.clnu.2015.03.016 | Intervention/Exposure
858 | Hernández-Mijares, A, Bañuls, C, Rocha, M, et al. Effects of phytosterol ester-enriched low-fat milk on serum lipoprotein profile in mildly hypercholesterolaemic patients are not related to dietary cholesterol or saturated fat intake. British journal of nutrition. 2010. 104:1018-1025. doi:10.1017/S0007114510001686 | Intervention/Exposure
859 | Héroux, M, Janssen, I, Lam, M, et al. Dietary patterns and the risk of mortality: impact of cardiorespiratory fitness. Int J Epidemiol. 2010. 39:197-209. doi:10.1093/ije/dyp191 | Intervention/Exposure
860 | Higdon JV, Du SH, Lee YS, Wu T, Wander RC. Supplementation of postmenopausal women with fish oil does not increase overall oxidation of LDL ex vivo compared to dietary oils rich in oleate and linoleate. J Lipid Res. 2001;42(3):407-418. | Intervention/Exposure; Sample size/Power
861 | Hikmat, F, Appel, LJ. Effects of the DASH diet on blood pressure in patients with and without metabolic syndrome: results from the DASH trial. Journal of Human Hypertension. Mar 2014;28(3):170-175. doi:10.1038/jhh.2013.52 | Intervention/Exposure
862 | Hilary Green, J, Richards, JK, Bunning, RL. Blood pressure responses to high-calcium skim milk and potassium-enriched high-calcium skim milk. J Hypertens. Sep 2000;18(9):1331-9. doi:10.1097/00004872-200018090-00020 | Intervention/Exposure; Comparator
863 | Hill, AM, Harris Jackson, KA, Roussell, MA, et al. Type and amount of dietary protein in the treatment of metabolic syndrome: a randomized controlled trial. Am J Clin Nutr. 2015. 102:757-70. doi:10.3945/ajcn.114.104026 | Intervention/Exposure
864 | Hilpert, K. Effects of dairy products on blood pressure, endothelial function, lipids and lipoproteins, and intracellular ion dynamics in Caucasian adults with stage 1 hypertension [Dissertation]. Pennsylvania State University. 2005. | Publication status
865 | Hilpert, KF, Kris-Etherton, PM, West, SG. Lipid response to a low-fat diet with or without soy is modified by C-reactive protein status in moderately hypercholesterolemic adults. Journal of Nutrition. May 2005;135(5):1075-1079. doi:DOI 10.1093/jn/135.5.1075 | Intervention/Exposure
866 | Hilpert, KF, West, SG, Bagshaw, DM, et al. Effects of dairy products on intracellular calcium and blood pressure in adults with essential hypertension. J Am Coll Nutr. Apr 2009;28(2):142-9. doi:10.1080/07315724.2009.10719765 | Health status; Sample size/Power
867 | Hinderliter, AL, Smith, P, Sherwood, A, et al. Lifestyle Interventions Reduce the Need for Guideline-Directed Antihypertensive Medication. American Journal of Hypertension. 2021. 34:1100-1107. doi:10.1093/ajh/hpab090 | Intervention/Exposure
868 | Hirahatake, KM, Jiang, L, Wong, ND, et al. Diet Quality and Cardiovascular Disease Risk in Postmenopausal Women With Type 2 Diabetes Mellitus: The Women’s Health Initiative. J Am Heart Assoc. 2019. 8:e013249. doi:10.1161/jaha.119.013249 | Intervention/Exposure; Health status
869 | Hirai, K, Ozeki, Y, Nakano, T, et al. A butter diet induces higher levels of n-3 PUFA and of n-3/n-6 PUFA ratio in rat serum and hearts than a safflower oil diet. Environ Health Prev Med. 2001. 5:138-43. doi:10.1007/bf02918289 | Non-human
870 | Hjerkinn, EM, Sandvik, L, Hjermann, I, et al. Effect of diet intervention on long-term mortality in healthy middle-aged men with combined hyperlipidaemia. J Intern Med. Jan 2004;255(1):68-73. doi:10.1046/j.0954-6820.2003.01248.x | Intervention/Exposure
871 | Hjerpsted, JB, Dragsted, LO, Tholstrup, T. Cheese intake in large amounts lowers LDL-cholesterol concentrations compared with butter intake of equal fat content. Am J Clin Nutr. Dec 2011;94(6):1479-84. doi:10.3945/ajcn.111.022426 | Sample size/Power
872 | HL Fateh, SA Rashid, SS Muhammad, SH Al-Jaf, AM Ali. Comparing effects of beetroot juice and Mediterranean diet on liver enzymes and sonographic appearance in patients with non-alcoholic fatty liver disease: a randomized control trials. Front Nutr. 2023 2023;10:1181706. doi:10.3389/fnut.2023.1181706 | Intervention/Exposure; Country
873 | Hlebowicz, J, Drake, I, Gullberg, B, et al. A high diet quality is associated with lower incidence of cardiovascular events in the Malmö diet and cancer cohort. PLoS One. 2013. 8:e71095. doi:10.1371/journal.pone.0071095 | Intervention/Exposure
874 | Hlebowicz, J, Persson, M, Gullberg, B, et al. Food patterns, inflammation markers and incidence of cardiovascular disease: the Malmo Diet and Cancer study. J Intern Med. Oct 2011;270(4):365-76. doi:10.1111/j.1365-2796.2011.02382.x | Intervention/Exposure
875 | Ho, FK, Gray, SR, Welsh, P, et al. Associations of fat and carbohydrate intake with cardiovascular disease and mortality: prospective cohort study of UK Biobank participants. Bmj. 2020. 368:m688. doi:10.1136/bmj.m688 | Intervention/Exposure
876 | Ho, YL, Nguyen, XMT, Yan, JQ, et al. Chocolate consumption and risk of coronary artery disease: the Million Veteran Program. Am J Clin Nutr. May 2021;113(5):1137-1144. doi:10.1093/ajcn/nqaa427 | Comparator
877 | Hobbs R. Risk of stroke in men is not associated with dietary fat intake. Evidence-based Healthcare. 2004;8(2):74-76. doi:10.1016/j.ehbc.2004.02.008 | Study design; Publication status
878 | Hochstenbach-Waelen, A, Soenen, S, Westerterp, KR, et al. Effects of a supra-sustained gelatin-milk protein diet compared with (supra-)sustained milk protein diets on body-weight loss. Br J Nutr. 2011. 105:1388-98. doi:10.1017/s0007114510005106 | Intervention/Exposure; Comparator
879 | Hodgson, JM, Burke, V, Beilin, LJ, et al. Partial substitution of carbohydrate intake with protein intake from lean red meat lowers blood pressure in hypertensive persons. Am J Clin Nutr. 2006. 83:780-7. doi:10.1093/ajcn/83.4.780 | Sample size/Power
880 | Hodgson, JM, Ward, NC, Burke, V, et al. Increased lean red meat intake does not elevate markers of oxidative stress and inflammation in humans. J Nutr. 2007. 137:363-7. doi:10.1093/jn/137.2.363 | Outcome
881 | Hodgson, JM, Zhu, K, Lewis, JR, et al. Long-term effects of a protein-enriched diet on blood pressure in older women. Br J Nutr. Jun 2012;107(11):1664-72. doi:10.1017/S0007114511004740 | Intervention/Exposure
882 | Hodson, L, Harnden, KE, Roberts, R, et al. Does the DASH diet lower blood pressure by altering peripheral vascular function? Journal of Human Hypertension. May 2010;24(5):312-319. doi:10.1038/jhh.2009.65 | Intervention/Exposure; Sample size/Power
883 | Hoevenaar-Blom, MP, Nooyens, AC, Kromhout, D, et al. Mediterranean style diet and 12-year incidence of cardiovascular diseases: the EPIC-NL cohort study. PLoS One. 2012. 7:e45458. doi:10.1371/journal.pone.0045458 | Intervention/Exposure
884 | Hoevenaar-Blom, MP, Spijkerman, AMW, Boshuizen, HC, et al. Effect of using repeated measurements of a Mediterranean style diet on the strength of the association with cardiovascular disease during 12 years: the Doetinchem Cohort Study. Eur J Nutr. Aug 2014;53(5):1209-15. doi:10.1007/s00394-013-0621-8 | Intervention/Exposure
885 | Holligan, SD, West, SG, Gebauer, SK, et al. A moderate-fat diet containing pistachios improves emerging markers of cardiometabolic syndrome in healthy adults with elevated LDL levels. Br J Nutr. Sep 14 2014;112(5):744-52. doi:10.1017/S0007114514001561 | Intervention/Exposure; Sample size/Power
886 | Holme, I, Retterstøl, K, Norum, KR, et al. Lifelong benefits on myocardial infarction mortality: 40-year follow-up of the randomized Oslo diet and antismoking study. J Intern Med. Aug 2016;280(2):221-7. doi:10.1111/joim.12485 | Intervention/Exposure
887 | Hong, S, Song, Y, Lee, KH, et al. A fruit and dairy dietary pattern is associated with a reduced risk of metabolic syndrome. Metabolism: Clinical and Experimental. 2012. 61:883-890. doi:10.1016/j.metabol.2011.10.018 | Intervention/Exposure
888 | Hooshmand, F, Asghari, G, Yuzbashian, E, et al. Modified Healthy Eating Index and Incidence of Metabolic Syndrome in Children and Adolescents: Tehran Lipid and Glucose Study. J Pediatr. Jun 2018;197:134-139 e2. doi:10.1016/j.jpeds.2018.01.080 | Outcome
889 | Horikawa, C, Kamada, C, Tanaka, S, et al. Meat intake and incidence of cardiovascular disease in Japanese patients with type 2 diabetes: analysis of the Japan Diabetes Complications Study (JDCS). Eur J Nutr. Feb 2019;58(1):281-290. doi:10.1007/s00394-017-1592-y | Health status
890 | Horvath, PJ, Eagen, CK, Fisher, NM, et al. The effects of varying dietary fat on performance and metabolism in trained male and female runners. J Am Coll Nutr. Feb 2000;19(1):52-60. doi:10.1080/07315724.2000.10718914 | Intervention/Exposure; Sample size/Power
891 | Hoşcan, Y, Yiğit, F, Müderrisoğlu, H. Adherence to Mediterranean diet and its relation with cardiovascular diseases in Turkish population. Int J Clin Exp Med. 2015;8(2):2860-6. | Study design; Intervention/Exposure
892 | Hoshino M, Soejima Y, Maeda Y, Ogata T. Lowering capacity of chocolate containing plant sterol on the serum cholesterol levels in subjects with borderline-high cholesterol or mild hypercholesterolemia - Optimal dose finding trial. Japanese Pharmacology and Therapeutics. 2012;40(9):795-805. | Publication language; Comparator
893 | Hosseini, Z, Rostami, M, Whiting, SJ, et al. Fast-Food Dietary Pattern Is Linked to Higher Prevalence of Metabolic Syndrome in Older Canadian Adults. Article. Journal of Nutrition and Metabolism. Oct 21 2021;2021doi:Artn 571284410.1155/2021/5712844 | Study design; Intervention/Exposure
894 | Hosseini-Esfahani, F, Koochakpoor, G, Tahmasebinejad, Z, et al. The association of dietary macronutrients composition with the incidence of cardiovascular disease, using iso-energetic substitution models: Tehran lipid and glucose study. Nutrition Metabolism and Cardiovascular Diseases. Nov 27 2020;30(12):2186-2193. doi:10.1016/j.numecd.2020.07.017 | Intervention/Exposure
895 | Hosseini-Esfahani, F, Mirmiran, P, Daneshpour, MS, et al. Western dietary pattern interaction with APOC3 polymorphism in the risk of metabolic syndrome: Tehran Lipid and Glucose Study. J Nutrigenet Nutrigenomics. 2014;7(2):105-17. doi:10.1159/000365445 | Intervention/Exposure
896 | Hosseinpour-Niazi, S, Bakhshi, B, Mirmiran, P, et al. Effect of weight change on the association between overall and source of carbohydrate intake and risk of metabolic syndrome: Tehran lipid and glucose study. Nutrition & Metabolism. Sep 12 2023;20(1)doi:ARTN 3910.1186/s12986-023-00761-0 | Intervention/Exposure
897 | Hosseinpour-Niazi, S, Mirmiran, P, Hedayati, M, et al. Substitution of red meat with legumes in the therapeutic lifestyle change diet based on dietary advice improves cardiometabolic risk factors in overweight type 2 diabetes patients: a cross-over randomized clinical trial. Eur J Clin Nutr. 2015. 69:592-7. doi:10.1038/ejcn.2014.228 | Health status
898 | Hosseinpour-Niazi, S, Mirmiran, P, Hosseini-Esfahani, F, et al. Is the metabolic syndrome inversely associates with butter, non-hydrogenated- and hydrogenated-vegetable oils consumption: Tehran lipid and glucose study. Diabetes Research and Clinical Practice. Feb 2016;112:20-29. doi:10.1016/j.diabres.2015.11.008 | Intervention/Exposure; Comparator
899 | Høstmark AT, Lunde MS. Cheese can reduce indexes that estimate fatty acid desaturation. Results from the Oslo Health Study and from experiments with human hepatoma cells. Appl Physiol Nutr Metab. 2012;37(1):31-39. doi:10.1139/h11-123 | Outcome
900 | Høstmark AT, Tomten SE. The Oslo health study: cheese intake was negatively associated with the metabolic syndrome. J Am Coll Nutr. 2011;30(3):182-190. doi:10.1080/07315724.2011.10719959 | Study design
901 | Høstmark AT. The Oslo Health Study: a Dietary Index estimating high intake of soft drinks and low intake of fruits and vegetables was positively associated with components of the metabolic syndrome. Appl Physiol Nutr Metab. 2010;35(6):816-825. doi:10.1139/H10-080 | Study design; Intervention/Exposure
902 | Hou IC, Suzuki A, Nakagawa K, Kurokawa M. Effects of a food containing chicken collagen hydrolysate on blood pressure and vascular endothelial function in subjects with high-normal blood pressure and stage I hypertension: - A randomized, double-blind, parallel-group, placebo-controlled trial. Japanese Pharmacology and Therapeutics. 2017;45(8):1333-1343. | Intervention/Exposure
903 | Houston, DK, Driver, KE, Bush, AJ, et al. The association between cheese consumption and cardiovascular risk factors among adults. Journal of Human Nutrition and Dietetics. Apr 2008;21(2):129-140. doi:DOI 10.1111/j.1365-277X.2008.00853.x | Study design
904 | Howard, BV, Curb, JD, Eaton, CB, et al. Low-fat dietary pattern and lipoprotein risk factors: the Women’s Health Initiative Dietary Modification Trial. American journal of clinical nutrition. 2010. 91:860-874. doi:10.3945/ajcn.2009.28034 | Intervention/Exposure
905 | Howard, BV, Hannah, JS, Heiser, CC, et al. Effects of sex and ethnicity on responses to a low-fat diet: a study of African Americans and whites. Am J Clin Nutr. Aug 1995;62(2):488S-492S. doi:10.1093/ajcn/62.2.488S | Intervention/Exposure; Sample size/Power
906 | Howard, BV, Hannah, JS, Heiser, CC, et al. Polyunsaturated Fatty-Acids Result in Greater Cholesterol-Lowering and Less Triacylglycerol Elevation Than Do Monounsaturated Fatty-Acids in a Dose-Response Comparison in a Multiracial Study-Group. American Journal of Clinical Nutrition. Aug 1995;62(2):392-402. doi:DOI 10.1093/ajcn/62.2.392 | Intervention/Exposure
907 | Howard, BV, Van Horn, L, Hsia, J, et al. Low-fat dietary pattern and risk of cardiovascular disease: the Women’s Health Initiative Randomized Controlled Dietary Modification Trial. JAMA. 2006. 295:655-666. doi:10.1001/jama.295.6.655 | Intervention/Exposure
908 | Howard, BV. Dietary fat and cardiovascular disease: putting the Women’s Health Initiative in perspective. Nutr Metab Cardiovasc Dis. Mar 2007;17(3):171-4. doi:10.1016/j.numecd.2006.10.006 | Study design
909 | Hshieh, TT, Petrone, AB, Gaziano, JM, et al. Nut consumption and risk of mortality in the Physicians’ Health Study. Am J Clin Nutr. Feb 2015;101(2):407-12. doi:10.3945/ajcn.114.099846 | Intervention/Exposure
910 | Hsia, J, Rodabough, RJ, Manson, JE, et al. Evaluation of the American Heart Association cardiovascular disease prevention guideline for women. Circ Cardiovasc Qual Outcomes. Mar 2010;3(2):128-34. doi:10.1161/CIRCOUTCOMES.108.842385 | Intervention/Exposure
911 | Htun, NC, Suga, H, Imai, S, et al. Dietary pattern and its association with blood pressure and blood lipid profiles among Japanese adults in the 2012 Japan National Health and Nutrition Survey. Asia Pac J Clin Nutr. 2018. 27:1048-1061. doi:10.6133/apjcn.072018.04 | Study design; Intervention/Exposure
912 | Htun, NC, Suga, H, Imai, S, et al. Food intake patterns and cardiovascular risk factors in Japanese adults: analyses from the 2012 National Health and nutrition survey, Japan. Nutr J. 2017. 16:61. doi:10.1186/s12937-017-0284-z | Study design; Intervention/Exposure
913 | Hu, EA, Anderson, CAM, Crews, DC, et al. A Healthy Beverage Score and Risk of Chronic Kidney Disease Progression, Incident Cardiovascular Disease, and All-Cause Mortality in the Chronic Renal Insufficiency Cohort. Curr Dev Nutr. 2020. 4:nzaa088. doi:10.1093/cdn/nzaa088 | Health status
914 | Hu, EA, Steffen, LM, Coresh, J, et al. Adherence to the Healthy Eating Index-2015 and Other Dietary Patterns May Reduce Risk of Cardiovascular Disease, Cardiovascular Mortality, and All-Cause Mortality. J Nutr. 2020. 150:312-321. doi:10.1093/jn/nxz218 | Intervention/Exposure
915 | Hu, FB, Rimm, EB, Stampfer, MJ, et al. Prospective study of major dietary patterns and risk of coronary heart disease in men. American Journal of Clinical Nutrition. 2000. 72:912-921. doi:10.1093/ajcn/72.4.912 | Intervention/Exposure
916 | Hu, FB, Stampfer, MJ, Manson, JE, et al. Dietary fat intake and the risk of coronary heart disease in women. N Engl J Med. Nov 20 1997;337(21):1491-9. doi:10.1056/NEJM199711203372102 | Intervention/Exposure
917 | Hu, FB, Stampfer, MJ, Manson, JE, et al. Dietary intake of α-linolenic acid and risk of fatal ischemic heart disease among women. American Journal of Clinical Nutrition. May 1999;69(5):890-897. | Intervention/Exposure
918 | Hu, FB, Stampfer, MJ, Manson, JE, et al. Frequent nut consumption and risk of coronary heart disease in women: prospective cohort study. BMJ. Nov 14 1998;317(7169):1341-5. doi:10.1136/bmj.317.7169.1341 | Intervention/Exposure
919 | Hu, FB, Stampfer, MJ, Manson, JE, et al. Dietary protein and risk of ischemic heart disease in women. Am J Clin Nutr. Aug 1999;70(2):221-7. doi:10.1093/ajcn.70.2.221 | Intervention/Exposure
920 | Hu, FB, Stampfer, MJ, Rimm, E, et al. Dietary fat and coronary heart disease: a comparison of approaches for adjusting for total energy intake and modeling repeated dietary measurements. Am J Epidemiol. Mar 15 1999;149(6):531-40. doi:10.1093/oxfordjournals.aje.a009849 | Intervention/Exposure
921 | Hu, MJ, Tan, JS, Gao, XJ, et al. Effect of Cheese Intake on Cardiovascular Diseases and Cardiovascular Biomarkers. Nutrients. Jul 18 2022;14(14)doi:10.3390/nu14142936 | Comparator
922 | Hu, P, Li, Y, Campos, H. Fried food intake and risk of nonfatal acute myocardial infarction in the Costa Rica Heart Study. PLoS One. 2018. 13:e0192960. doi:10.1371/journal.pone.0192960 | Study design; Intervention/Exposure
923 | Hu, T, Yao, L, Reynolds, K, et al. Adherence to low-carbohydrate and low-fat diets in relation to weight loss and cardiovascular risk factors. Obes Sci Pract. 2016. 2:24-31. doi:10.1002/osp4.23 | Intervention/Exposure
924 | Hu, T, Yao, L, Reynolds, K, et al. The Effects of a Low-Carbohydrate Diet vs. a Low-Fat Diet on Novel Cardiovascular Risk Factors: A Randomized Controlled Trial. Nutrients. 2015. 7:7978-94. doi:10.3390/nu7095377 | Intervention/Exposure
925 | Huang YC, Luedecke LO, Shultz TD. Effect of cheddar cheese consumption on plasma conjugated linoleic acid concentrations in men. Nutrition Research. 1994;14(3):373-386. doi: 10.1016/S0271-5317(05)80176-9 | Sample size/Power
926 | Huang, J, Liao, LM, Weinstein, SJ, et al. Association Between Plant and Animal Protein Intake and Overall and Cause-Specific Mortality. JAMA Intern Med. 2020. 180:1173-1184. doi:10.1001/jamainternmed.2020.2790 | Intervention/Exposure
927 | Huang, LN, Wang, HJ, Wang, ZH, et al. Association of Red Meat Usual Intake with Serum Ferritin and the Risk of Metabolic Syndrome in Chinese Adults: A Longitudinal Study from the China Health and Nutrition Survey. Biomed Environ Sci. 2020. 33:19-29. doi:10.3967/bes2020.003 | Outcome; Country
928 | Huang, LY, Wahlqvist, ML, Huang, YC, et al. Optimal Dairy Intake Is Predicated on Total, Cardiovascular, and Stroke Mortalities in a Taiwanese Cohort. Journal of the American College of Nutrition. Nov 2 2014;33(6):426-436. doi:10.1080/07315724.2013.875328 | Country
929 | Huang, X, Hui, H, Zhu, W, et al. Effect of the interaction between alcohol and meat consumption on the hyperlipidaemia risk among elderly individuals: Evidence from Shanghai, China. Front Nutr. 2022. 9:982626. doi:10.3389/fnut.2022.982626 | Study design; No confounder adjustment
930 | Hudson, JL, Zhou, J, Kim, JE, et al. Incorporating Milk Protein Isolate into an Energy-Restricted Western-Style Eating Pattern Augments Improvements in Blood Pressure and Triglycerides, but Not Body Composition Changes in Adults Classified as Overweight or Obese: A Randomized Controlled Trial. Nutrients. Mar 22 2020;12(3)doi:10.3390/nu12030851. | Intervention/Exposure
931 | Huffman, KM, Hawk, VH, Henes, ST, et al. Exercise effects on lipids in persons with varying dietary patterns-does diet matter if they exercise? Responses in Studies of a Targeted Risk Reduction Intervention through Defined Exercise I. Am Heart J. 2012. 164:117-24. doi:10.1016/j.ahj.2012.04.014 | Intervention/Exposure
932 | Huijbregts, PP, Feskens, EJ, Kromhout, D. Dietary patterns and cardiovascular risk factors in elderly men: the Zutphen Elderly Study. Int J Epidemiol. Apr 1995;24(2):313-20. doi:10.1093/ije/24.2.313 | Study design; Intervention/Exposure
933 | Hulander, E, Bärebring, L, Turesson Wadell, A, et al. Diet intervention improves cardiovascular profile in patients with rheumatoid arthritis: results from the randomized controlled cross-over trial ADIRA. Nutr J. 2021. 20:9. doi:10.1186/s12937-021-00663-y | Intervention/Exposure; Health status
934 | Humphries, SE, Talmud, PJ, Cox, C, et al. Genetic factors affecting the consistency and magnitude of changes in plasma cholesterol in response to dietary challenge. QJM. Sep 1996;89(9):671-80. doi:10.1093/qjmed/89.9.671 | Intervention/Exposure
935 | Hunninghake DB, Maki KC, Kwiterovich PO Jr, Davidson MH, Dicklin MR, Kafonek SD. Incorporation of lean red meat into a National Cholesterol Education Program Step I diet: A long-term, randomized clinical trial in free-living persons with hypercholesterolemia. Journal of the American College of Nutrition. Jun 2000;19(3):351-360. doi:Doi 10.1080/07315724.2000.10718931 | Intervention/Exposure
936 | Hunninghake, DB, Stein, EA, Dujovne, CA, et al. The efficacy of intensive dietary therapy alone or combined with lovastatin in outpatients with hypercholesterolemia. N Engl J Med. Apr 29 1993;328(17):1213-9. doi:10.1056/NEJM199304293281701 | Intervention/Exposure; Comparator
937 | Hwang DH, Chanmugam PS, Ryan DH, et al. Does vegetable oil attenuate the beneficial effects of fish oil in reducing risk factors for cardiovascular disease?. Am J Clin Nutr. 1997;66(1):89-96. doi:10.1093/ajcn/66.1.89 | Intervention/Exposure
938 | Hwang, JY, Lee, H, Ko, A, et al. Dietary changes in Vietnamese marriage immigrant women: The KoGES follow-up study. Nutr Res Pract. 2014. 8:319-26. doi:10.4162/nrp.2014.8.3.319 | Study design; Intervention/Exposure; Outcome
939 | Hyde, PN, Sapper, TN, Crabtree, CD, et al. Dietary carbohydrate restriction improves metabolic syndrome independent of weight loss. JCI Insight. Jun 20 2019;4(12)doi:10.1172/jci.insight.128308 | Intervention/Exposure; Sample size/Power
940 | Hyde, PN, Sapper, TN, LaFountain, RA, et al. Effects of Palm Stearin versus Butter in the Context of Low-Carbohydrate/High-Fat and High-Carbohydrate/Low-Fat Diets on Circulating Lipids in a Controlled Feeding Study in Healthy Humans. Nutrients. Jun 5 2021;13(6)doi:10.3390/nu13061944 | Duration
941 | Ibsen, DB, Christiansen, AH, Olsen, A, et al. Adherence to the EAT-Lancet Diet and Risk of Stroke and Stroke Subtypes: A Cohort Study. Stroke. 2022. 53:154-163. doi:10.1161/STROKEAHA.121.036738 | Intervention/Exposure
942 | Ibsen, DB, Jakobsen, MU, Halkjær, J, et al. Replacing Red Meat with Other Nonmeat Food Sources of Protein is Associated with a Reduced Risk of Type 2 Diabetes in a Danish Cohort of Middle-Aged Adults. J Nutr. 2021. 151:1241-1248. doi:10.1093/jn/nxaa448 | Outcome
943 | Ibsen, DB, Søgaard, K, Sørensen, LH, et al. Modifiable Lifestyle Recommendations and Mortality in Denmark: A Cohort Study. American Journal of Preventive Medicine. 2021. 60:792-801. doi:10.1016/j.amepre.2021.01.003 | Intervention/Exposure
944 | Iggman, D, Rosqvist, F, Larsson, A, et al. Role of dietary fats in modulating cardiometabolic risk during moderate weight gain: a randomized double-blind overfeeding trial (LIPOGAIN study). J Am Heart Assoc. 2014. 3:e001095. doi:10.1161/jaha.114.001095 | Sample size/Power
945 | Igl, W, Kamal-Eldin, A, Johansson, A, et al. Animal source food intake and association with blood cholesterol, glycerophospholipids and sphingolipids in a northern Swedish population. Int J Circumpolar Health. 2013;72doi:10.3402/ijch.v72i0.21162 | Study design
946 | Ikem, E, Halldorsson, TI, Birgisdóttir, BE, et al. Dietary patterns and the risk of pregnancy-associated hypertension in the Danish National Birth Cohort: a prospective longitudinal study. Bjog. 2019. 126:663-673. doi:10.1111/1471-0528.15593 | Intervention/Exposure; Outcome
947 | Ilich, JZ, Liu, PY, Shin, H, et al. ardiometabolic Indices after Weight Loss with Calcium or Dairy Foods: Secondary Analyses from a Randomized Trial with Overweight/Obese Postmenopausal Women. Nutrients. Mar 4 2022;14(5)doi:10.3390/nu14051082 | Intervention/Exposure; Comparator
948 | Inoue, K, Shirai, T, Ochiai, H, et al. Blood-pressure-lowering effect of a novel fermented milk containing gamma-aminobutyric acid (GABA) in mild hypertensives. Eur J Clin Nutr. 2003. 57:490-5. doi:10.1038/sj.ejcn.1601555 | Intervention/Exposure; Comparator
949 | Insull Jr, W, Silvers, A, Hicks, L, et al. Plasma lipid effects of three common vegetable oils in reduced-fat diets of free-living adults. Am J Clin Nutr. Aug 1994;60(2):195-202. doi:10.1093/ajcn/60.2.195 | Intervention/Exposure
950 | Insull, W, Jr, Henderson, MM, Prentice, et al Results of a randomized feasibility study of a low-fat diet. Arch Intern Med. Feb 1990;150(2):421-7. | Intervention/Exposure
951 | Intorre, F, Foddai, MS, Azzini, E, et al. Differential effect of cheese fatty acid composition on blood lipid profile and redox status in normolipidemic volunteers: a pilot study. Int J Food Sci Nutr. Sep 2011;62(6):660-9. doi:10.3109/09637486.2011.569491 | Intervention/Exposure; Comparator
952 | Intorre, F, Venneria, E, Finotti, E, et al. Fatty acid content of serum lipid fractions and blood lipids in normolipidaemic volunteers fed two types of cheese having different fat compositions: a pilot study. International Journal of Food Sciences and Nutrition. Mar 2013;64(2):185-193. doi:10.3109/09637486.2012.710893 | Comparator; Sample size/Power
953 | Iqbal, R, Dehghan, M, Mente, A, et al. Associations of unprocessed and processed meat intake with mortality and cardiovascular disease in 21 countries [Prospective Urban Rural Epidemiology (PURE) Study]: a prospective cohort study. Am J Clin Nutr. 2021. 114:1049-1058. doi:10.1093/ajcn/nqaa448 | Comparator
954 | Ishinaga, M, Sugiyama, S, Mochizuki, T. Daily intakes of fatty acids, sterols, and phospholipids by Japanese women and serum cholesterol. J Nutr Sci Vitaminol (Tokyo). Dec 1994;40(6):557-67. doi:10.3177/jnsv.40.557 | Intervention/Exposure
955 | Iso, H, Imano, H, Nakagawa, Y, et al. One-year community-based education program for hypercholesterolemia in middle-aged Japanese: a long-term outcome at 8-year follow-up. Atherosclerosis. 2002. 164:195-202. doi:10.1016/s0021-9150(02)00064-3 | Intervention/Exposure
956 | Iso, H, Konishi, M, Terao, A, et al. [A community-based education program for serum cholesterol reduction in urban hypercholesterolemic persons-comparison of intensive and usual education groups]. Nihon Koshu Eisei Zasshi. Sep 1991;38(9):751-61. | Publication language
957 | Iso, H, Kubota, Y. Nutrition and disease in the Japan Collaborative Cohort Study for Evaluation of Cancer (JACC). Asian Pac J Cancer Prev. 2007;8 Suppl:35-80. | Intervention/Exposure
958 | Iso, H, Stampfer, MJ, Manson, JE, et al. Prospective study of fat and protein intake and risk of intraparenchymal hemorrhage in women. Circulation. Feb 13 2001;103(6):856-63. doi:10.1161/01.cir.103.6.856 | Intervention/Exposure
959 | Itakura H, Ikemoto S, Terada S, Kondo K. The Effect of Sour Milk on Blood Pressure in Untreated Hypertensive and Normotensive Subjects. Journal of Japanese Society of Clinical Nutrition. 2001;23:26-31. | Study design; Publication language
960 | Ivey KL, Nguyen XT, Li R, et al. Association of dietary fatty acids with the risk of atherosclerotic cardiovascular disease in a prospective cohort of United States veterans. Am J Clin Nutr. 2023;118(4):763-772. doi:10.1016/j.ajcnut.2023.07.014 | Intervention/Exposure
961 | Ivey, KL, Hodgson, JM, Kerr, DA, et al. The effect of yoghurt and its probiotics on blood pressure and serum lipid profile; a randomised controlled trial. Nutr Metab Cardiovasc Dis. Jan 2015;25(1):46-51. doi:10.1016/j.numecd.2014.07.012 | Intervention/Exposure
962 | Ivey, KL, Lewis, JR, Hodgson, JM, et al. Association between yogurt, milk, and cheese consumption and common carotid artery intima-media thickness and cardiovascular disease risk factors in elderly women. Am J Clin Nutr. 2011. 94:234-9. doi:10.3945/ajcn.111.014159 | Intervention/Exposure; Comparator
963 | Ivey, KL, Nguyen, XMT, Tobias, DK, et al. Dietary yogurt is distinct from other dairy foods in its association with circulating lipid profile: Findings from the Million Veteran Program. Clinical Nutrition ESPEN. 2021. 43:456-463. doi:10.1016/j.clnesp.2021.02.022 | Comparator
964 | J Dukuzimana, S Janzi, C Habberstad, S Zhang, Y Borné, E Sonestedt. High consumption of dairy products and risk of major adverse coronary events and stroke in a Swedish population. Br J Nutr. Feb 14 2024;131(3):500-511. doi:10.1017/S0007114523001939 | Comparator
965 | J Park, DK Lee, A Sharma, HJ Lee. An eight-week randomized intervention study on Korean adults to evaluate the effect of milk intake on obesity. J Dairy Sci. Dec 2023;106(12):8262-8271. doi:10.3168/jds.2022-23212 | Comparator
966 | Jaafari AA, Tahbaz F, Majd HA, Joodaki H. Comparison of the effect of a probiotic yoghurt and ordinary yoghurt on serum cholesterol levels in subjects with mild to moderate hypercholesterolemia. Iranian Journal of Diabetes and Lipid Disorders. 2005; 4(3):E6+E6i-E6vi. | Intervention/Exposure
967 | Jaakkola, JM, Pahkala, K, Rönnemaa, T, et al. Longitudinal child-oriented dietary intervention: Association with parental diet and cardio-metabolic risk factors. The Special Turku Coronary Risk Factor Intervention Project. Eur J Prev Cardiol. 2017. 24:1779-1787. doi:10.1177/2047487317720286 | Intervention/Exposure
968 | Jääskeläinen, P, Magnussen, CG, Pahkala, K, et al. Childhood nutrition in predicting metabolic syndrome in adults: the cardiovascular risk in Young Finns Study. Diabetes Care. 2012. 35:1937-43. doi:10.2337/dc12-0019 | Intervention/Exposure; Outcome
969 | Jaček, M, Hrnčířová, D, Rambousková, J, et al. Effect of Food with Low Enrichment of N-3 Fatty Acids in a Two-Month Diet on the Fatty Acid Content in the Plasma and Erythrocytes and on Cardiovascular Risk Markers in Healthy Young Men. Nutrients. Jul 24 2020;12(8)doi:10.3390/nu12082207 | Intervention/Exposure; Sample size/Power
970 | Jacques, H, Gascon, A, Arul, J, et al. Modified milk fat reduces plasma triacylglycerol concentrations in normolipidemic men compared with regular milk fat and nonhydrogenated margarine. Am J Clin Nutr. Dec 1999;70(6):983-91. doi:10.1093/ajcn/70.6.983 | Sample size/Power
971 | Jacques, H, Laurin, D, Moorjani, S, et al. Influence of diets containing cow’s milk or soy protein beverage on plasma lipids in children with familial hypercholesterolemia. J Am Coll Nutr. Jun 1992;11 Suppl:69S-73S. doi:10.1080/07315724.1992.10737988 | Study design; Sample size/Power
972 | Jacques, H, Noreau, L, Moorjani, S. Effects on plasma lipoproteins and endogenous sex hormones of substituting lean white fish for other animal-protein sources in diets of postmenopausal women. Am J Clin Nutr. Apr 1992;55(4):896-901. doi:10.1093/ajcn/55.4.896 | Intervention/Exposure; Sample size/Power
973 | Jakobsen MU, Overvad K, Dyerberg J, Heitmann BL. Intake of ruminant trans fatty acids and risk of coronary heart disease. Int J Epidemiol. 2008;37(1):173-182. doi:10.1093/ije/dym243 | Intervention/Exposure
974 | Jakobsen, MU, Dethlefsen, C, Joensen, AM, et al. Intake of carbohydrates compared with intake of saturated fatty acids and risk of myocardial infarction: importance of the glycemic index. Am J Clin Nutr. 2010. 91:1764-8. doi:10.3945/ajcn.2009.29099 | Intervention/Exposure
975 | Jakobsen, MU, Overvad, K, Dyerberg, J, et al. Dietary fat and risk of coronary heart disease: possible effect modification by gender and age. Am J Epidemiol. 2004. 160:141-9. doi:10.1093/aje/kwh193 | Intervention/Exposure
976 | Jancey J, Holt AM, Lee A, et al. Effects of a physical activity and nutrition program in retirement villages: a cluster randomised controlled trial [published correction appears in Int J Behav Nutr Phys Act. 2017 Sep 21;14(1):129. doi: 10.1186/s12966-017-0568-x]. Int J Behav Nutr Phys Act. 2017;14(1):92. doi:10.1186/s12966-017-0543-6 | Intervention/Exposure
977 | Jankovic, N, Geelen, A, Streppel, MT, et al. WHO guidelines for a healthy diet and mortality from cardiovascular disease in European and American elderly: the CHANCES project. Am J Clin Nutr. 2015. 102:745-56. doi:10.3945/ajcn.114.095117 | Intervention/Exposure
978 | Jansen, S, López-Miranda, J, Castro, P, et al. Low-fat and high-monounsaturated fatty acid diets decrease plasma cholesterol ester transfer protein concentrations in young, healthy, normolipemic men. Am J Clin Nutr. Jul 2000;72(1):36-41. doi:10.1093/ajcn/72.1.36 | Intervention/Exposure
979 | Jansen, S, Lopez-Miranda, J, Ordovas, JM, et al. Effect of 360His mutation in apolipoprotein A-IV on plasma HDL-cholesterol response to dietary fat. J Lipid Res. Oct 1997;38(10):1995-2002. | Intervention/Exposure
980 | Jansen, S, Lopez-Miranda, J, Salas, J, et al. Plasma lipid response to hypolipidemic diets in young healthy non-obese men varies with body mass index. J Nutr. Jul 1998;128(7):1144-9. doi:10.1093/jn/128.7.1144 | Intervention/Exposure
981 | Janszky, I, Mukamal, KJ, Ljung, R, et al. Chocolate consumption and mortality following a first acute myocardial infarction: the Stockholm Heart Epidemiology Program. J Intern Med. Sep 2009;266(3):248-57. doi:10.1111/j.1365-2796.2009.02088.x | Health status
982 | Janus, ED, Best, JD, Davis-Lameloise, N, et al. Scaling-up from an implementation trial to state-wide coverage: results from the preliminary Melbourne Diabetes Prevention Study. Trials. 2012. 13:152. doi:10.1186/1745-6215-13-152 | Intervention/Exposure
983 | Jaross W, Bergmann S, Wahrburg U, Schulte H, Assmann G. Dietary habits in Eastern Germany: changes after reunification and their relation to CHD risk profiles (DRECAN). Rev Environ Health. 1996;11(1-2):27-33. doi:10.1515/reveh.1996.11.1-2.27 | Intervention/Exposure
984 | Jassim AM, Mohammad SS, Ridha AMA. A study of dietary pattern toward ischemic heart disease among patients under 50 years old. Indian Journal of Public Health Research & Development. 2018;9(8):1135-1141. | Study design; Outcome
985 | Jauhiainen, T, Salo, P, Niittynen, L, et al. Effects of low-fat hard cheese enriched with plant stanol esters on serum lipids and apolipoprotein B in mildly hypercholesterolaemic subjects. Eur J Clin Nutr. 2006. 60:1253-7. doi:10.1038/sj.ejcn.1602445 | Comparator
986 | Jauhiainen, T, Vapaatalo, H, Poussa, T, et al. Lactobacillus helveticus fermented milk lowers blood pressure in hypertensive subjects in 24-h ambulatory blood pressure measurement. Am J Hypertens. 2005. 18:1600-5. doi:10.1016/j.amjhyper.2005.06.006 | Intervention/Exposure; Comparator
987 | Jebb, SA, Lovegrove, JA, Griffin, BA, et al. Effect of changing the amount and type of fat and carbohydrate on insulin sensitivity and cardiovascular risk: the RISCK (Reading, Imperial, Surrey, Cambridge, and Kings) trial. Am J Clin Nutr. 2010. 92:748-58. doi:10.3945/ajcn.2009.29096 | Intervention/Exposure
988 | Jeffery, RW, Wing, RR, French, SA. Weight cycling and cardiovascular risk factors in obese men and women. Am J Clin Nutr. Mar 1992;55(3):641-4. doi:10.1093/ajcn/55.3.641 | Intervention/Exposure
989 | Jehn, ML, Patt, MR, Appel, LJ, et al. One year follow-up of overweight and obese hypertensive adults following intensive lifestyle therapy. J Hum Nutr Diet. Oct 2006;19(5):349-54. doi:10.1111/j.1365-277X.2006.00711.x | Intervention/Exposure
990 | Jenkins, DJ, Chiavaroli, L, Wong, JM, et al. Adding monounsaturated fatty acids to a dietary portfolio of cholesterol-lowering foods in hypercholesterolemia. CMAJ. Dec 14 2010;182(18):1961-7. doi:10.1503/cmaj.092128 | Intervention/Exposure
991 | Jenkins, DJ, Jones, PJ, Lamarche, B, et al. Effect of a Dietary Portfolio of Cholesterol-Lowering Foods Given at 2 Levels of Intensity of Dietary Advice on Serum Lipids in Hyperlipidemia A Randomized Controlled Trial. Jama-Journal of the American Medical Association. Aug 24 2011;306(8):831-839. doi:10.1001/jama.2011.1202 | Intervention/Exposure
992 | Jenkins, DJ, Kendall, CW, Connelly, PW, et al. Effects of high- and low-isoflavone (phytoestrogen) soy foods on inflammatory biomarkers and proinflammatory cytokines in middle-aged men and women. Metabolism. Jul 2002;51(7):919-24. doi:10.1053/meta.2002.33352 | Intervention/Exposure; Comparator
993 | Jenkins, DJ, Kendall, CW, Faulkner, D, et al. A dietary portfolio approach to cholesterol reduction: combined effects of plant sterols, vegetable proteins, and viscous fibers in hypercholesterolemia. Metabolism. Dec 2002;51(12):1596-604. doi:10.1053/meta.2002.35578 | Intervention/Exposure; Sample size/Power
994 | Jenkins, DJ, Kendall, CW, Jackson, CJ, et al. Effects of high- and low-isoflavone soyfoods on blood lipids, oxidized LDL, homocysteine, and blood pressure in hyperlipidemic men and women. Am J Clin Nutr. Aug 2002;76(2):365-72. doi:10.1093/ajcn/76.2.365 | Intervention/Exposure
995 | Jenkins, DJ, Kendall, CW, Marchie, A, et al. Effects of a dietary portfolio of cholesterol-lowering foods vs lovastatin on serum lipids and C-reactive protein. JAMA. Jul 23 2003;290(4):502-10. doi:10.1001/jama.290.4.502 | Intervention/Exposure
996 | Jenkins, DJ, Kendall, CW, Marchie, A, et al. The effect of combining plant sterols, soy protein, viscous fibers, and almonds in treating hypercholesterolemia. Metabolism. 2003. 52:1478-83. doi:10.1016/s0026-0495(03)00260-9 | Intervention/Exposure
997 | Jenkins, DJ, Kendall, CW, Vidgen, E, et al. The effect on serum lipids and oxidized low-density lipoprotein of supplementing self-selected low-fat diets with soluble-fiber, soy, and vegetable protein foods. Metabolism: clinical and experimental. 2000. 49:67-72. doi:10.1016/s0026-0495(00)90738-8 | Sample size/Power
998 | Jenkins, DJ, Wong, JM, Kendall, CW, et al. The effect of a plant-based lowcarbohydrate (“Eco-Atkins”) diet on body weight and blood lipid concentrations in hyperlipidemic subjects. Arch Intern Med. Jun 8 2009;169(11):1046-54. doi:10.1001/archinternmed.2009.115 | Intervention/Exposure
999 | Jeong, J, Lim, K, Shin, S. The association between meat intake and the risk of coronary heart disease in Korean men using the Framingham risk score: A prospective cohort study. Nutr Metab Cardiovasc Dis. 2023. 33:1158-1166. doi:10.1016/j.numecd.2023.02.001 | Comparator
1000 | Jeppesen, J, Schaaf, P, Jones, C, et al. Effects of low-fat, high-carbohydrate diets on risk factors for ischemic heart disease in postmenopausal women. Am J Clin Nutr. Apr 1997;65(4):1027-33. doi:10.1093/ajcn/65.4.1027 | Intervention/Exposure
1001 | Jessri, M, Hennessey, D, Bader Eddeen, A, et al. Sodium, added sugar and saturated fat intake in relation to mortality and CVD events in adults: Canadian National Nutrition Survey linked with vital statistics and health administrative databases. Br J Nutr. 2023. 129:1740-1750. doi:10.1017/s000711452200099x | Intervention/Exposure
1002 | Jeyakumar, SM, Damayanti, K, Rajkumar Ponday, L, et al. Assessment of virgin coconut oil in a balanced diet on indicators of cardiovascular health in non-obese volunteers: A human metabolic study. Diabetes Metab Syndr. 2023. 17:102844. doi:10.1016/j.dsx.2023.102844 | Country
1003 | Jiang, J, Liu, M, Troy, LM, et al. Concordance with DASH diet and blood pressure change: results from the Framingham Offspring Study (1991-2008). J Hypertens. Nov 2015;33(11):2223-30. doi:10.1097/HJH.0000000000000710 | Intervention/Exposure; Comparator
1004 | Jiang, R, Manson, JE, Stampfer, MJ, et al. Nut and peanut butter consumption and risk of type 2 diabetes in women. Jama. 2002. 288:2554-60. doi:10.1001/jama.288.20.2554 | Intervention/Exposure; Outcome
1005 | Jiang, W, Song, Q, Zhang, J, et al. The Association of Consumption Time for Food With Cardiovascular Disease and All-Cause Mortality Among Diabetic Patients. J Clin Endocrinol Metab. 2022. 107:e3066-e3075. doi:10.1210/clinem/dgac069 | Health status
1006 | Jin Y, Georgalos A, Vanstone C, et al. Effect of Dairy Fat Consumption on Insulin Sensitivity in People With Overweight or Obesity With Prediabetes: a 12-Week Randomized Controlled Trial Protocol. Curr Dev Nutr. 2023;7:101729. doi:10.1016/j.cdnut.2023.101729 | Study design; Publication status
1007 | Jin, JL, Cao, YX, Liu, HH, et al. Impact of free fatty acids on prognosis in coronary artery disease patients under different glucose metabolism status. Cardiovasc Diabetol. Oct 14 2019;18(1):134. doi:10.1186/s12933-019-0936-8 | Intervention/Exposure; Health status
1008 | Jin, S, Je, Y. Dairy Consumption and Risk of Metabolic Syndrome in Korean Adults and Elderly People. Metab Syndr Relat Disord. Jun 2021;19(5):272-280. doi:10.1089/met.2020.0122 | Study design
1009 | Jin, Y, Kanaya, AM, Kandula, NR, et al. Vegetarian Diets Are Associated with Selected Cardiometabolic Risk Factors among Middle-Older Aged South Asians in the United States. Journal of Nutrition. Dec 2018;148(12):1954-1960. doi:10.1093/jn/nxy217 | Study design; Intervention/Exposure
1010 | Jing H, Teng Y, Chacha S, et al. Is Increasing Diet Diversity of Animal-Source Foods Related to Better Health-Related Quality of Life among Chinese Men and Women?. Nutrients. 2023;15(19):4183. doi:10.3390/nu15194183 | Intervention/Exposure; Outcome
1011 | Jo, G, Park, D, Lee, J, et al. Trends in Diet Quality and Cardiometabolic Risk Factors Among Korean Adults, 2007-2018. JAMA Netw Open. 2022. 5:e2218297. doi:10.1001/jamanetworkopen.2022.18297 | Study design
1012 | Johansson, A, Acosta, S, Mutie, PM, et al. Components of a healthy diet and different types of physical activity and risk of atherothrombotic ischemic stroke: A prospective cohort study. Front Cardiovasc Med. 2022. 9:993112. doi:10.3389/fcvm.2022.993112 | Comparator
1013 | Johansson, A, Acosta, S. Diet and Lifestyle as Risk Factors for Carotid Artery Disease: A Prospective Cohort Study. Cerebrovasc Dis. 2020. 49:563-569. doi:10.1159/000510907 | Intervention/Exposure
1014 | Johansson, I, Esberg, A, Nilsson, LM, et al. Dairy Product Intake and Cardiometabolic Diseases in Northern Sweden: A 33-Year Prospective Cohort Study. Nutrients. 2019. 11:284. doi:10.3390/nu11020284 | Comparator
1015 | Johansson, I, Nilsson, LM, Esberg, A, et al. Dairy intake revisited - associations between dairy intake and lifestyle related cardio-metabolic risk factors in a high milk consuming population. Nutr J. 2018. 17:110. doi:10.1186/s12937-018-0418-y | Comparator
1016 | Johansson, J, Viigimaa, M, Jensen-Urstad, M, et al. Risk factors for coronary heart disease in 55- and 35-year-old men and women in Sweden and Estonia. J Intern Med. Dec 2002;252(6):551-60. doi:10.1046/j.1365-2796.2002.01068.x | Study design; Comparator
1017 | Johns, DJ, Lindroos, AK, Jebb, SA, et al. Dietary patterns, cardiometabolic risk factors, and the incidence of cardiovascular disease in severe obesity. Obesity (Silver Spring). 2015. 23:1063-70. doi:10.1002/oby.20920 | Intervention/Exposure
1018 | Johnson LK, Hjermann I, Tonstad S. Kosthold og sekundaerforebygging av koronar hjertesykdom-er våre anbefalinger gode nok? [Diet and secondary prevention of coronary heart disease-are our recommendations good enough?]. Tidsskr Nor Laegeforen. 2001;121(9):1092-1098. | Study design; Publication language
1019 | Johnson, ES, Zhou, Y. Non-cancer mortality in supermarket meat workers. J Occup Environ Med. Aug 2007;49(8):846-52. doi:10.1097/JOM.0b013e3180cac1f1 | Study design; Intervention/Exposure
1020 | Johnston EA, Petersen KS, Kris-Etherton PM. Daily intake of non-fried potato does not affect markers of glycaemia and is associated with better diet quality compared with refined grains: a randomised, crossover study in healthy adults. Br J Nutr. 2020;123(9):1032-1042. doi:10.1017/S0007114520000252 | Intervention/Exposure
1021 | Johnston, CS, Tjonn, SL, Swan, PD, et al. Ketogenic low-carbohydrate diets have no metabolic advantage over nonketogenic low-carbohydrate diets. American Journal of Clinical Nutrition. May 2006;83(5):1055-1061. doi:DOI 10.1093/ajcn/83.5.1055 | Intervention/Exposure
1022 | Jones, JL, Sabaté, J, Heskey, C, et al. Macadamia nut effects on cardiometabolic risk factors: a randomised trial. J Nutr Sci. 2023. 12:e55. doi:10.1017/jns.2023.39 | Intervention/Exposure
1023 | Jones, KW, Eller, LK, Parnell, JA, et al. Effect of a dairy-and calcium-rich diet on weight loss and appetite during energy restriction in overweight and obese adults: A randomized trial. European Journal of Clinical Nutrition. 2013. 67:371-376. doi:10.1038/ejcn.2013.52 | Intervention/Exposure; Comparator
1024 | Jones, NRV, Forouhi, NG, Khaw, KT, et al. Accordance to the Dietary Approaches to Stop Hypertension diet pattern and cardiovascular disease in a British, population-based cohort. European Journal of Epidemiology. 2018. 33:235-244. doi:10.1007/s10654-017-0354-8 | Intervention/Exposure
1025 | Jones, PJ, Lichtenstein, AH, Schaefer, EJ, et al. Effect of dietary fat selection on plasma cholesterol synthesis in older, moderately hypercholesterolemic humans. Arterioscler Thromb. Apr 1994;14(4):542-8. doi:10.1161/01.atv.14.4.542 | Duration; Sample size/Power
1026 | Jones, PJ, Lichtenstein, AH, Schaefer, EJ. Interaction of dietary fat saturation and cholesterol level on cholesterol synthesis measured using deuterium incorporation. J Lipid Res. Jun 1994;35(6):1093-101. | Sample size/Power
1027 | Jönsson, T, Granfeldt, Y, Ahrén, B, et al. Beneficial effects of a Paleolithic diet on cardiovascular risk factors in type 2 diabetes: a randomized cross-over pilot study. Cardiovasc Diabetol. 2009. 8:35. doi:10.1186/1475-2840-8-35 | Health status
1028 | Jontez N, Novak K, Kenig S, Petelin A, Jenko Pražnikar Z, Mohorko N. The Impact of COVID-19-Related Lockdown on Diet and Serum Markers in Healthy Adults. Nutrients. 2021;13(4):1082. doi:10.3390/nu13041082 | Intervention/Exposure; No confounder adjustment
1029 | Joo SJ, Kies C, Schnepf M. Chocolate and chocolate-like products: Impact on serum lipid profiles and serum fatty acid composition of humans. Journal of Applied Nutrition. 1997;49(3): 46-55. | Duration; Sample size/Power
1030 | Joo, NS, Yang, SW, Park, SJ, et al. Milk Consumption and Framingham Risk Score: Analysis of the Korea National Health and Nutrition Examination Survey Data (2008-2011). Yonsei Med J. 2016. 57:197-202. doi:10.3349/ymj.2016.57.1.197 | Study design
1031 | Jorde, R, Bonaa, KH. Calcium from dairy products, vitamin D intake, and blood pressure: the Tromso Study. Am J Clin Nutr. Jun 2000;71(6):1530-5. doi:10.1093/ajcn/71.6.1530 | Intervention/Exposure
1032 | Joris, PJ, Plat, J, Kusters, YHAM, et al. Effects of diet-induced weight loss on postprandial vascular function after consumption of a mixed meal: Results of a randomized controlled trial with abdominally obese men. Clinical Nutrition. 2020. 39:2998-3004. doi:10.1016/j.clnu.2020.01.006 | Intervention/Exposure; Sample size/Power
1033 | Joyce, T, Wallace, AJ, McCarthy, SN, et al. Intakes of total fat, saturated, monounsaturated and polyunsaturated fatty acids in Irish children, teenagers and adults. Public Health Nutrition. 2009. 12:156-165. doi:10.1017/S1368980008002772 | Study design
1034 | Judd, JT, Baer, DJ, Chen, SC, et al. Plant sterol esters lower plasma lipids and most carotenoids in mildly hypercholesterolemic adults. Lipids. Jan 2002;37(1):33-42. doi:DOI 10.1007/s11745-002-0861-y | Intervention/Exposure; Duration
1035 | Judd, JT, Baer, DJ, Clevidence, BA, et al. Dietary cis and trans monounsaturated and saturated FA and plasma lipids and lipoproteins in men. Lipids. Feb 2002;37(2):123-31. doi:10.1007/s11745-002-0871-9 | Intervention/Exposure
1036 | Jula A, Rönnemaa T, Rastas M, Karvetti RL, Mäki J. Long-term nopharmacological treatment for mild to moderate hypertension. J Intern Med. 1990;227(6):413-421. doi:10.1111/j.1365-2796.1990.tb00180.x | Intervention/Exposure
1037 | Jula A, Rönnemaa T, Rastas M, Karvetti RL, Mäki J. Long-term nopharmacological treatment for mild to moderate hypertension. J Intern Med. 1990;227(6):413-421. doi:10.1111/j.1365-2796.1990.tb00180.x | Intervention/Exposure
1038 | Jula, A, Marniemi, J, Huupponen, R, et al. Effects of diet and simvastatin on serum lipids, insulin, and antioxidants in hypercholesterolemic men: a randomized controlled trial. JAMA. Feb 6 2002;287(5):598-605. doi:10.1001/jama.287.5.598 | Intervention/Exposure; Comparator
1039 | Julibert, A, Bibiloni, MDM, Bouzas, C, et al. Total and Subtypes of Dietary Fat Intake and Its Association with Components of the Metabolic Syndrome in a Mediterranean Population at High Cardiovascular Risk. Nutrients. Jul 2019;11(7)doi:ARTN 1493 10.3390/nu11071493 | Intervention/Exposure
1040 | Jung, H, Chen, CYO, Blumberg, JB, et al. The effect of almonds on vitamin E status and cardiovascular risk factors in Korean adults: a randomized clinical trial. European Journal of Nutrition. 2018. 57:2069-2079. doi:10.1007/s00394-017-1480-5 | Intervention/Exposure
1041 | Jung, H, Lee, G, Lim, K, et al. Association of milk consumption with management and incidence of hypertension among South Korean adults: A prospective analysis of the health examinees study cohort. Nutr Metab Cardiovasc Dis. 2022. 32:2515-2525. doi:10.1016/j.numecd.2022.07.022 | Intervention/Exposure; Comparator
1042 | Jung, K, Kim, S, Woo, J, et al. The effect of dietary intervention through the modification of fatty acids composition and antioxidant vitamin intake on plasma TXB(2) level in Korean postmenopausal women with hypercholesterolemia. J Korean Med Sci. 2002. 17:307-15. doi:10.3346/jkms.2002.17.3.307 | Intervention/Exposure; Comparator
1043 | Júnior FAO, Ruiz CR, de Oliveira Y, et al. Coconut Oil Supplementation Does Not Affect Blood Pressure Variability and Oxidative Stress: A Placebo-Controlled Clinical Study in Stage-1 Hypertensive Patients. Nutrients. 2021;13(3):798. Published 2021 Feb 28. doi:10.3390/nu13030798 | Health status; Comparator
1044 | Juraschek, SP, Kovell, LC, Appel, LJ, et al. Associations Between Dietary Patterns and Subclinical Cardiac Injury: An Observational Analysis From the DASH Trial. Ann Intern Med. 2020. 172:786-794. doi:10.7326/m20-0336 | Intervention/Exposure
1045 | Juraschek, SP, Miller, ER, 3rd, Weaver, et al. Effects of Sodium Reduction and the DASH Diet in Relation to Baseline Blood Pressure. J Am Coll Cardiol. 2017. 70:2841-2848. doi:10.1016/j.jacc.2017.10.011 | Intervention/Exposure
1046 | Juraschek, SP, Yokose, C, McCormick, N, et al. Effects of Dietary Patterns on Serum Urate: Results From a Randomized Trial of the Effects of Diet on Hypertension. Arthritis Rheumatol. 2021. 73:1014-1020. doi:10.1002/art.41614 | Intervention/Exposure
1047 | Juul, L, Andersen, VJ, Arnoldsen, J, et al. Effectiveness of a brief theory-based health promotion intervention among adults at high risk of type 2 diabetes: One-year results from a randomised trial in a community setting. Prim Care Diabetes. 2016. 10:111-20. doi:10.1016/j.pcd.2015.07.002 | Intervention/Exposure
1048 | Kabagambe, EK, Baylin, A, Ascherio, A, et al. The type of oil used for cooking is associated with the risk of nonfatal acute myocardial infarction in costa rica. J Nutr. 2005. 135:2674-9. doi:10.1093/jn/135.11.2674 | Study design
1049 | Kagawa T, Ohgami N, He T, et al. Elevated arsenic level in fasting serum via ingestion of fish meat increased the risk of hypertension in humans and mice. Eur Heart J Open. 2023;3(5):oead074. Published 2023 Sep 4. doi:10.1093/ehjopen/oead074 | Intervention/Exposure
1050 | Kaitosaari, T, Rönnemaa, T, Raitakari, O, et al. Effect of 7-year infancy-onset dietary intervention on serum lipoproteins and lipoprotein subclasses in healthy children in the prospective, randomized Special Turku Coronary Risk Factor Intervention Project for Children (STRIP) study. Circulation. Aug 12 2003;108(6):672-7. doi:10.1161/01.CIR.0000083723.75065.D4 | Intervention/Exposure
1051 | Kajimoto O, Furusawa K, Aoi S, Oshima H. Effects of soymilk containing soy protein on human serum cholesterol in normal and borderline hypercholesterolemia subjects. Japanese Pharmacology and Therapeutics. 2006;34(1):119-134. | Publication language
1052 | Kajimoto O, Nakamura Y, Yada H, Moriguchi M, Hirata H, Takahashi T. Hypotensive effects of sour milk in subjects with mild or moderate hypertension. Journal of Japan Society of Nutrition and Food Science. 2001;54(6):347-354. doi:10.4327/jsnfs.54.347 | Publication language
1053 | Kalkuz, S, Demircan, A. Effects of the Mediterranean diet adherence on body composition, blood parameters and quality of life in adults. Postgrad Med J. Dec 2021;97(1154):798-802. doi:10.1136/postgradmedj-2020-138667 | Study design; Intervention/Exposure
1054 | Kaluza, J, . Long-term processed and unprocessed red meat consumption and risk of heart failure: A prospective cohort study of women. Int J Cardiol. Aug 15 2015;193:42-6. doi:10.1016/j.ijcard.2015.05.044 | Comparator
1055 | Kaluza, J, Akesson, A, Wolk, A. Processed and unprocessed red meat consumption and risk of heart failure: prospective study of men. Circ Heart Fail. Jul 2014;7(4):552-7. doi:10.1161/CIRCHEARTFAILURE.113.000921 | Comparator
1056 | Kamath, SK, Ravishanker, C, Briones, E, et al. Macronutrient intake and blood cholesterol level of a community of Asian Indians living in the United States. J Am Diet Assoc. 1997. 97:299-301. doi:10.1016/s0002-8223(97)00078-3 | Study design; Comparator
1057 | Kang, Y, Kim, J. Association between fried food consumption and hypertension in Korean adults. Br J Nutr. 2016. 115:87-94. doi:10.1017/s000711451500402x | Study design; Intervention/Exposure
1058 | Kant, AK, Graubard, BI. A comparison of three dietary pattern indexes for predicting biomarkers of diet and disease. J Am Coll Nutr. 2005. 24:294-303. doi:10.1080/07315724.2005.10719477 | Intervention/Exposure
1059 | Kant, AK, Leitzmann, MF, Park, Y, et al. Patterns of recommended dietary behaviors predict subsequent risk of mortality in a large cohort of men and women in the United States. J Nutr. 2009. 139:1374-80. doi:10.3945/jn.109.104505 | Intervention/Exposure; Outcome
1060 | Kant, AK, Schatzkin, A, Graubard, BI, et al. A prospective study of diet quality and mortality in women. JAMA. Apr 26 2000;283(16):2109-15. doi:10.1001/jama.283.16.2109 | Intervention/Exposure
1061 | Kant, AK, Schatzkin, A, Ziegler, RG. Dietary diversity and subsequent cause-specific mortality in the NHANES I epidemiologic follow-up study. J Am Coll Nutr. Jun 1995;14(3):233-8. doi:10.1080/07315724.1995.10718501 | Intervention/Exposure
1062 | Kappeler, R, Eichholzer, M, Rohrmann, S. Meat consumption and diet quality and mortality in NHANES III. Eur J Clin Nutr. 2013. 67:598-606. doi:10.1038/ejcn.2013.59 | Comparator
1063 | Karanja, NM, Obarzanek, E, Lin, PH, et al. Descriptive characteristics of the dietary patterns used in the Dietary Approaches to Stop Hypertension Trial. DASH Collaborative Research Group. J Am Diet Assoc. 1999. 99:S19-27. doi:10.1016/s0002-8223(99)00412-5 | Intervention/Exposure; Outcome
1064 | Karatzi K, Aissopou EK, Tsirimiagou C, Fatmeli E, Sfikakis PP, Protogerou AD. Association of consumption of dairy products and meat with retinal vessel calibers in subjects at increased cardiovascular risk. Nutr Metab Cardiovasc Dis. 2016;26(8):752-757. doi:10.1016/j.numecd.2016.03.006 | Study design; Outcome
1065 | Karppanen, H, Mervaala, E. Adherence to and population impact of non-pharmacological and pharmacological antihypertensive therapy. J Hum Hypertens. Feb 1996;10 Suppl 1:S57-61. | Intervention/Exposure
1066 | Kasai M, Nosaka N, Maki H, et al. Effect of dietary medium- and long-chain triacylglycerols (MLCT) on accumulation of body fat in healthy humans. Asia Pac J Clin Nutr. 2003;12(2):151-160. | Intervention/Exposure
1067 | Kasim-Karakas, SE, Lane, E, Almario, R, et al. Effects of dietary fat restriction on particle size of plasma lipoproteins in postmenopausal women. Metabolism. Apr 1997;46(4):431-6. doi:10.1016/s0026-0495(97)90061-5 | Study design; Intervention/Exposure; Sample size/Power
1068 | Kassymov S, Blagov D, Mironova I, et al. Role of chicken meat in human diet. Int J Pharmaceutical Research. 2019;11:701-703. | Study design; Intervention/Exposure
1069 | Katz, DL, Evans, MA, Nawaz, H, et al. Egg consumption and endothelial function: a randomized controlled crossover trial. Int J Cardiol. 2005. 99:65-70. doi:10.1016/j.ijcard.2003.11.028 | Intervention/Exposure
1070 | Kaul, N, Kreml, R, Austria, JA, et al. A comparison of fish oil, flaxseed oil and hempseed oil supplementation on selected parameters of cardiovascular health in healthy volunteers. J Am Coll Nutr. Feb 2008;27(1):51-8. doi:10.1080/07315724.2008.10719674 | Intervention/Exposure
1071 | Kaunitz H, Dayrit CS. Coconut oil consumption and coronary heart disease. Philipp J Intern Med. 1992;30:165-171. | Study design
1072 | Kawamura, A, Kajiya, K, Kishi, H, et al. The Nutritional Characteristics of the Hypotensive WASHOKU-modified DASH Diet: A Sub-analysis of the DASH-JUMP Study. Curr Hypertens Rev. 2018. 14:56-65. doi:10.2174/1573402114666180405100430 | Intervention/Exposure
1073 | Kazemi, A, Sasani, N, Mokhtari, Z, et al. Comparing the risk of cardiovascular diseases and all-cause mortality in four lifestyles with a combination of high/low physical activity and healthy/unhealthy diet: a prospective cohort study. Int J Behav Nutr Phys Act. Nov 16 2022;19(1):138. doi:10.1186/s12966-022-01374-1 | Intervention/Exposure
1074 | Keaver L, Ruan M, Chen F, et al. Plant- and animal-based diet quality and mortality among US adults: a cohort study. Br J Nutr. 2021;125(12):1405-1415. doi:10.1017/S0007114520003670 | Intervention/Exposure
1075 | Kelemen, LE, Kushi, LH, Jacobs, DR, et al. Associations of dietary protein with disease and mortality in a prospective study of postmenopausal women. Am J Epidemiol. 2005. 161:239-49. doi:10.1093/aje/kwi038 | Intervention/Exposure
1076 | Kelishadi R, Zemel MB, Hashemipour M, Hosseini M, Mohammadifard N, Poursafa P. Can a dairy-rich diet be effective in long-term weight control of young children?. J Am Coll Nutr. 2009;28(5):601-610. doi:10.1080/07315724.2009.10719792 | Intervention/Exposure; Comparator
1077 | Kelishadi, R, Gouya, MM, Adeli, K, et al. Factors associated with the metabolic syndrome in a national sample of youths: CASPIAN Study. Nutr Metab Cardiovasc Dis. Sep 2008;18(7):461-70. doi:10.1016/j.numecd.2007.02.014 | Study design
1078 | Kelly, FD, Mann, NJ, Turner, AH, et al. Stearic acid-rich diets do not increase thrombotic risk factors in healthy males. Lipids. 1999. 34 Suppl:S199. doi:10.1007/bf02562288 | Outcome; Publication status; Sample size/Power
1079 | Kelly, FD, Sinclair, AJ, Mann, NJ, et al. A stearic acid-rich diet improves thrombogenic and atherogenic risk factor profiles in healthy males. Eur J Clin Nutr. 2001. 55:88-96. doi:10.1038/sj.ejcn.1601122 | Sample size/Power
1080 | Kendall, CW, West, SG, Augustin, LS, et al. Acute effects of pistachio consumption on glucose and insulin, satiety hormones and endothelial function in the metabolic syndrome. Eur J Clin Nutr. Mar 2014;68(3):370-5. doi:10.1038/ejcn.2013.275 | Intervention/Exposure
1081 | Keogh JB, Luscombe-Marsh ND, Noakes M, Wittert GA, Clifton PM. Long-term weight maintenance and cardiovascular risk factors are not different following weight loss on carbohydrate-restricted diets high in either monounsaturated fat or protein in obese hyperinsulinaemic men and women. Br J Nutr. 2007;97(2):405-410. doi:10.1017/S0007114507252687 | Intervention/Exposure
1082 | Keogh, JB, Brinkworth, GD, Noakes, M, et al. Effects of weight loss from a very-low-carbohydrate diet on endothelial function and markers of cardiovascular disease risk in subjects with abdominal obesity. Am J Clin Nutr. Mar 2008;87(3):567-76. doi:10.1093/ajcn/87.3.567 | Intervention/Exposure
1083 | Keogh, JB, Clifton, P. The effect of meal replacements high in glycomacropeptide on weight loss and markers of cardiovascular disease risk. Am J Clin Nutr. 2008. 87:1602-5. doi:10.1093/ajcn/87.6.1602 | Intervention/Exposure
1084 | Kerver, JM, Eun, JY, Bianchi, L, et al. Dietary patterns associated with risk factors for cardiovascular disease in healthy US adults. American Journal of Clinical Nutrition. 2003. 78:1103-1110. doi:10.1093/ajcn/78.6.1103 | Study design; Intervention/Exposure
1085 | Keshavarz, SA, Nourieh, Z, Attar, MJ, et al. Effect of Soymilk Consumption on Waist Circumference and Cardiovascular Risks among Overweight and Obese Female Adults. Int J Prev Med. Nov 2012;3(11):798-805. | Sample size/Power
1086 | Keshavarz, Z, Rahimlou, M, Farjam, M, et al. Non-alcoholic fatty liver disease and dairy products consumption: Results from FASA Persian cohort study. Front Nutr. 2022. 9:962834. doi:10.3389/fnut.2022.962834 | Study design; Outcome
1087 | Kesse-Guyot, E, Fezeu, L, Galan, P, et al. Adherence to French Nutritional Guidelines Is Associated with Lower Risk of Metabolic Syndrome. Journal of Nutrition. Jun 2011;141(6):1134-1139. doi:10.3945/jn.110.136317 | Intervention/Exposure
1088 | Kesse-Guyot, E, Touvier, M, Henegar, A, et al. Higher adherence to French dietary guidelines and chronic diseases in the prospective SU.VI.MAX cohort. Eur J Clin Nutr. Aug 2011;65(8):887-94. doi:10.1038/ejcn.2011.61 | Intervention/Exposure
1089 | Ketomäki, AM, Gylling, H, Antikainen, M, et al. Red cell and plasma plant sterols are related during consumption of plant stanol and sterol ester spreads in children with hypercholesterolemia. J Pediatr. 2003. 142:524-31. doi:10.1067/mpd.2003.193 | Intervention/Exposure; Comparator
1090 | Keys, A, Menott, A, Karvonen, MJ, et al. The diet and 15-year death rate in the seven countries study. Am J Epidemiol. Dec 1986;124(6):903-15. doi:10.1093/oxfordjournals.aje.a114480 | Intervention/Exposure
1091 | Khan, N, Monagas, M, Andres-Lacueva, C, et al. Regular consumption of cocoa powder with milk increases HDL cholesterol and reduces oxidized LDL levels in subjects at high-risk of cardiovascular disease. Nutr Metab Cardiovasc Dis. 2012. 22:1046-53. doi:10.1016/j.numecd.2011.02.001 | Intervention/Exposure; Comparator
1092 | Khandouzi, N, Zahedmehr, A, Asadian, S, et al. Effects of olive oil and flaxseed consumption in a healthy diet on endothelial function, plasma lipids and inflammatory factors of patients with coronary heart disease: a randomized clinical trial. Coron Artery Dis. Aug 1 2023;34(5):332-340. doi:10.1097/MCA.0000000000001259 | Intervention/Exposure; Health status
1093 | Khaw, KT, Sharp, SJ, Finikarides, L, et al. Randomised trial of coconut oil, olive oil or butter on blood lipids and other cardiovascular risk factors in healthy men and women. BMJ Open. 2018. 8:e020167. doi:10.1136/bmjopen-2017-020167 | Sample size/Power
1094 | Khaw, KT. Dietary fat intake and coronary heart disease in women. Acta Cardiol. 1993;48(5):442-4. | Study design; Publication status
1095 | Khawaja, O, Petrone, AB, Kanjwal, Y, et al. Chocolate Consumption and Risk of Atrial Fibrillation (from the Physicians’ Health Study). Am J Cardiol. Aug 15 2015;116(4):563-6. doi:10.1016/j.amjcard.2015.05.009 | Outcome
1096 | Khorraminezhad, L, Rudkowska, I. Modulation of gene expression profile following consumption of high-dairy products in subjects with hyperinsulinemia. Nutrition, Metabolism and Cardiovascular Diseases. 2023. 33:219-226. doi:10.1016/j.numecd.2022.10.015 | Outcome; Sample size/Power
1097 | Khoury, J, Henriksen, T, Christophersen, B, et al. Effect of a cholesterol-lowering diet on maternal, cord, and neonatal lipids, and pregnancy outcome: a randomized clinical trial. Am J Obstet Gynecol. Oct 2005;193(4):1292-301. doi:10.1016/j.ajog.2005.05.016 | Intervention/Exposure
1098 | Kiage, JN, Merrill, PD, Judd, SE, et al. Intake of trans fat and incidence of stroke in the REasons for Geographic And Racial Differences in Stroke (REGARDS) cohort. Am J Clin Nutr. May 2014;99(5):1071-6. doi:10.3945/ajcn.113.075713 | Intervention/Exposure
1099 | Kiessling, G, Schneider, J, Jahreis, G. Long-term consumption of fermented dairy products over 6 months increases HDL cholesterol. Eur J Clin Nutr. 2002. 56:843-9. doi:10.1038/sj.ejcn.1601399 | Intervention/Exposure; Comparator
1100 | Kietsiriroje, N, Kwankaew, J, Kitpakornsanti, S, et al. Effect of phytosterols and inulinenriched soymilk on LDL-cholesterol in Thai subjects: a double-blinded randomized controlled trial. Lipids in health and disease. 2015. 14:146. doi:10.1186/s12944-015-0149-4 | Intervention/Exposure; Comparator
1101 | Kim, D, Kim, J. Dairy consumption is associated with a lower incidence of the metabolic syndrome in middle-aged and older Korean adults: the Korean Genome and Epidemiology Study (KoGES). Br J Nutr. 2017. 117:148-160. doi:10.1017/s000711451600444x | Intervention/Exposure; Comparator
1102 | Kim, H, Lee, K, Rebholz, CM, et al. Plant-based diets and incident metabolic syndrome: Results from a South Korean prospective cohort study. PLoS Med. 2020. 17:e1003371. doi:10.1371/journal.pmed.1003371 | Intervention/Exposure
1103 | Kim, H, Yoon, E, Kim, OY, et al. Short-term Effects of Eating Behavior Modification on Metabolic Syndrome-Related Risks in Overweight and Obese Korean Adults. J Obes Metab Syndr. Mar 30 2022;31(1):70-80. doi:10.7570/jomes21074 | Intervention/Exposure
1104 | Kim, HK, Kim, SH, Jang, CS, et al. The combined effects of yogurt and exercise in healthy adults: Implications for biomarkers of depression and cardiovascular diseases. Food Sci Nutr. 2018. 6:1968-1974. doi:10.1002/fsn3.772 | Duration
1105 | Kim, HY, Lee, J, Kim, J. Association between Dietary Inflammatory Index and Metabolic Syndrome in the General Korean Population. Nutrients. May 2018;10(5)doi:ARTN 64810.3390/nu10050648 | Study design
1106 | Kim, J, Jo, I. Grains, vegetables, and fish dietary pattern is inversely associated with the risk of metabolic syndrome in South korean adults. J Am Diet Assoc. 2011. 111:1141-9. doi:10.1016/j.jada.2011.05.001 | Study design
1107 | Kim, J, Kim, M, Shin, Y, et al. Association between Dietary Diversity Score and Metabolic Syndrome in Korean Adults: A Community-Based Prospective Cohort Study. Nutrients. Dec 2022;14(24)doi:ARTN 5298 | Intervention/Exposure
1108 | Kim, J. Dairy food consumption is inversely associated with the risk of the metabolic syndrome in Korean adults. Journal of Human Nutrition and Dietetics. Jul 2013;26:171-179. doi:10.1111/jhn.12098 | Study design
1109 | Kim, JY, Kim, OY, Koh, SJ, et al. Comparison of low-fat meal and high-fat meal on postprandial lipemic response in non-obese men according to the −1131T>C polymorphism of the apolipoprotein A5 (APOA5) gene (randomized cross-over design). J Am Coll Nutr. Aug 2006;25(4):340-7. doi:10.1080/07315724.2006.10719544 | Duration
1110 | Kim, SA, Shin, S. Dietary Patterns and the Risk of Dyslipidemia in Korean Adults: A Prospective Cohort Study Based on the Health Examinees (HEXA) Study. J Acad Nutr Diet. 2021. 121:1242-1257.e2. doi:10.1016/j.jand.2020.08.090 | Intervention/Exposure
1111 | Kim, SA, Shin, S. Red meat and processed meat consumption and the risk of dyslipidemia in Korean adults: A prospective cohort study based on the Health Examinees (HEXA) study. Nutr Metab Cardiovasc Dis. 2021. 31:1714-1727. doi:10.1016/j.numecd.2021.02.008 | Intervention/Exposure; Comparator
1112 | Kim, Y, Keogh, JB, Clifton, PM. Consumption of red and processed meat and refined grains for 4weeks decreases insulin sensitivity in insulin-resistant adults: A randomized crossover study. Metabolism. 2017. 68:173-183. doi:10.1016/j.metabol.2016.12.011 | Intervention/Exposure
1113 | Kim, Y, Keogh, JB, Clifton, PM. Differential Effects of Red Meat/Refined Grain Diet and Dairy/Chicken/Nuts/Whole Grain Diet on Glucose, Insulin and Triglyceride in a Randomized Crossover Study. Article. Nutrients. Oct 30 2016;8(11)doi:10.3390/nu8110687 | Intervention/Exposure; Duration
1114 | Kim, Y, Keogh, JB, Clifton, PM. Effects of Two Different Dietary Patterns on Inflammatory Markers, Advanced Glycation End Products and Lipids in Subjects without Type 2 Diabetes: A Randomised Crossover Study. Nutrients. Mar 29 2017;9(4)doi:10.3390/nu9040336 | Intervention/Exposure
1115 | Kim, Y, Kim, YM, Shin, MH, et al. Empirically identified dietary patterns and metabolic syndrome risk in a prospective cohort study: The Cardiovascular Disease Association Study. Clin Nutr. 2022. 41:2156-2162. doi:10.1016/j.clnu.2022.07.038 | Intervention/Exposure
1116 | Kim, Y, Lu, S, Ho, JE, et al. Proteins as Mediators of the Association Between Diet Quality and Incident Cardiovascular Disease and All-Cause Mortality: The Framingham Heart Study. Article. Journal of the American Heart Association. Sep 21 2021;10(18)doi:ARTN e02124510.1161/JAHA.121.021245 | Intervention/Exposure
1117 | Kim, YO. Dietary patterns associated with hypertension among Korean males. Nutr Res Pract. 2009. 3:162-6. doi:10.4162/nrp.2009.3.2.162 | Intervention/Exposure
1118 | Kimokoti, RW, Gona, P, Zhu, L, et al. Dietary patterns of women are associated with incident abdominal obesity but not metabolic syndrome. Journal of Nutrition. 2012. 142:1720-1727. doi:10.3945/jn.112.162479 | Intervention/Exposure
1119 | Kirk, JK, Craven, T, Lipkin, EW, et al. Longitudinal changes in dietary fat intake and associated changes in cardiovascular risk factors in adults with type 2 diabetes: the ACCORD trial. Diabetes Res Clin Pract. 2013. 100:61-8. doi:10.1016/j.diabres.2013.02.001 | Health status
1120 | Kishimoto, Y, Taguchi, C, Suzuki-Sugihara, N, et al. The Effect of the Consumption of Egg on Serum Lipids and Antioxidant Status in Healthy Subjects. J Nutr Sci Vitaminol (Tokyo). 2016. 62:361-365. doi:10.3177/jnsv.62.361 | Intervention/Exposure; Sample size/Power
1121 | Kityo, A, Lee, SA, Kang, D. Total and cause-specific mortality associated with meat intake in a large cohort study in Korea. Front Nutr. 2023. 10:1138102. doi:10.3389/fnut.2023.1138102 | Comparator
1122 | Kityo, A, Lee, SA. The intake of ultra-processed foods, all-cause, cancer and cardiovascular mortality in the Korean Genome and Epidemiology Study-Health Examinees (KoGES-HEXA) cohort. Article. PLoS One. 2023;18(5):e0285314. doi:10.1371/journal.pone.0285314 | Comparator
1123 | Kleber, ME, Delgado, GE, Dawczynski, C, et al. Saturated fatty acids and mortality in patients referred for coronary angiography-The Ludwigshafen Risk and Cardiovascular Health study. J Clin Lipidol. 2018. 12:455-463.e3. doi:10.1016/j.jacl.2018.01.007 | Intervention/Exposure
1124 | Kleemola, P, Puska, P, Vartiainen, E, et al. The effect of breakfast cereal on diet and serum cholesterol: a randomized trial in North Karelia, Finland. Eur J Clin Nutr. 1999. 53:716-21. doi:10.1038/sj.ejcn.1600849 | Intervention/Exposure; Comparator
1125 | Knopp, RH, Retzlaff, B, Fish, B, et al. Effects of insulin resistance and obesity on lipoproteins and sensitivity to egg feeding. Arterioscler Thromb Vasc Biol. Aug 1 2003;23(8):1437-43. doi:10.1161/01.ATV.0000082461.77557.C7 | Intervention/Exposure
1126 | Knopp, RH, Retzlaff, BM, Walden, CE, et al. A double-blind, randomized, controlled trial of the effects of two eggs per day in moderately hypercholesterolemic and combined hyperlipidemic subjects taught the NCEP step I diet. J Am Coll Nutr. Dec 1997;16(6):551-61. | Intervention/Exposure
1127 | Knopp, RH, Walden, CE, Retzlaff, BM, et al. Long-term cholesterol-lowering effects of 4 fat-restricted diets in hypercholesterolemic and combined hyperlipidemic men. The Dietary Alternatives Study. JAMA. Nov 12 1997;278(18):1509-15. | Intervention/Exposure
1128 | Knutsen, SF, Knutsen, R. The Tromso Survey - the Family Intervention Study - the Effect of Intervention on Some Coronary Risk-Factors and Dietary Habits, a 6-Year Follow-Up. Preventive Medicine. Mar 1991;20(2):197-212. doi:Doi 10.1016/00917435(91)90020-5 | Intervention/Exposure
1129 | Kobayashi, M, Sasazuki, S, Shimazu, T, et al. Association of dietary diversity with total mortality and major causes of mortality in the Japanese population: JPHC study. Eur J Clin Nutr. 2020. 74:54-66. doi:10.1038/s41430-019-0416-y | Comparator
1130 | Koebnick, C, Plank-Habibi, S, Wirsam, B, et al. Double-blind, randomized feedback control fails to improve the hypocholesterolemic effect of a plant-based low-fat diet in patients with moderately elevated total cholesterol levels. Eur J Clin Nutr. 2004. 58:1402-9. doi:10.1038/sj.ejcn.1601984 | Intervention/Exposure
1131 | Koemel, NA, Senior, AM, Celermajer, DS, et al. Multi-Nutrient Analysis of Dietary Macronutrients with All-Cause, Cardiovascular, and Cancer Mortality: Data from NHANES 1999–2014. Nutrients. 2023. 15:345. doi:10.3390/nu15020345 | Intervention/Exposure
1132 | Kohl, J, Brame, J, Hauff, P, et al. Effects of a Web-Based Weight Loss Program on the Healthy Eating Index-NVS in Adults with Overweight or Obesity and the Association with Dietary, Anthropometric and Cardiometabolic Variables: A Randomized Controlled Clinical Trial. Nutrients. Dec 20 2022;15(1)doi:10.3390/nu15010007 | Intervention/Exposure
1133 | Kolacek, S, Kapetanović, T, Luzar, V. Early determinants of cardiovascular risk factors in adults. B. Blood pressure. Acta Paediatr. Apr 1993;82(4):377-82. doi:10.1111/j.1651-2227.1993.tb12701.x | Intervention/Exposure
1134 | Koli, R, Köhler, K, Tonteri, E, et al. Dark chocolate and reduced snack consumption in mildly hypertensive adults: an intervention study. Nutr J. 2015. 14:84. doi:10.1186/s12937-015-0075-3 | Intervention/Exposure; Comparator; Sample size/Power
1135 | Kolobarić, N, Drenjančević, I, Matić, A, et al. Dietary Intake of n-3 PUFA-Enriched Hen Eggs Changes Inflammatory Markers’ Concentration and Treg/Th17 Cells Distribution in Blood of Young Healthy Adults-A Randomised Study. Nutrients. May 28 2021;13(6)doi:10.3390/nu13061851 | Intervention/Exposure
1136 | Kolovou, GD, Fostinis, YP, Athanassopoulos, G, et al. Differential Response of High-Density-Lipoproteins to First-Step Lipid-Lowering Diet According to Their Initial Level. Coronary Artery Disease. Apr 1994;5(4):359-364. doi:Doi 10.1097/00019501-199404000-00012 | Study design; Intervention/Exposure
1137 | Kondo, I, Funahashi, K, Nakamura, M, et al. Association between food group intake and serum total cholesterol in the Japanese population: NIPPON DATA 80/90. J Epidemiol. 2010. 20 Suppl 3:S576-81. doi:10.2188/jea.je20090227 | Study design
1138 | Kondo, I, Ojima, T, Nakamura, M, et al. Consumption of dairy products and death from cardiovascular disease in the Japanese general population: the NIPPON DATA80. J Epidemiol. 2013. 23:47-54. doi:10.2188/jea.je20120054 | Intervention/Exposure; Comparator
1139 | Konieczna, J, Romaguera, D, Pereira, V, et al. Longitudinal association of changes in diet with changes in body weight and waist circumference in subjects at high cardiovascular risk: the PREDIMED trial. International Journal of Behavioral Nutrition and Physical Activity. Dec 27 2019;16(1)doi:ARTN 139 10.1186/s12966-019-0893-3 | Outcome
1140 | Konishi, T, Takahashi, Y, Shiina, Y, et al. Time-of-day effects of consumption of fish oil–enriched sausages on serum lipid parameters and fatty acid composition in normolipidemic adults: A randomized, double-blind, placebo-controlled, and parallel-group pilot study. Nutrition. 2021. 90:111247. doi:10.1016/j.nut.2021.111247 | Sample size/Power
1141 | Kontogianni, MD, Panagiotakos, DB, Pitsavos, C, et al. Relationship between meat intake and the development of acute coronary syndromes: the CARDIO2000 case-control study. Eur J Clin Nutr. 2008. 62:171-7. doi:10.1038/sj.ejcn.1602713 | Study design
1142 | Kooyenga, DK, Geller, M, Watkins, TR, et al. Palm oil antioxidant effects in patients with hyperlipidaemia and carotid stenosis-2 year experience. Asia Pac J Clin Nutr. Mar 1997;6(1):72-5 | Health status
1143 | Kopčeková, J, Holovičová, M, Gažarová, M, et al. Association between Selected Dietary Habits and Lipid Profiles of Patients with Cardiovascular Disease. Int J Environ Res Public Health. Oct 19 2020;17(20)doi:10.3390/ijerph17207605 | Intervention/Exposure; Health status
1144 | Kordella, T. The joy of chocolate. Diabetes Forecast. Jul 2005;58(7):34. | Study design; Duration
1145 | Korhonen, M, Kastarinen, M, Uusitupa, M, et al. The effect of intensified diet counseling on the diet of hypertensive subjects in primary health care: a 2-year open randomized controlled trial of lifestyle intervention against hypertension in eastern Finland. Prev Med. Jan 2003;36(1):8-16. doi:10.1006/pmed.2002.1120 | Intervention/Exposure
1146 | Korpela, R, Tuomilehto, J, Högström, P, et al. Safety aspects and cholesterollowering efficacy of low fat dairy products containing plant sterols. European journal of clinical nutrition. 2006. 60:633-642. doi:10.1038/sj.ejcn.1602362 | Comparator
1147 | Korrapati, D, Jeyakumar, SM, Putcha, UK, et al. Coconut oil consumption improves fat-free mass, plasma HDL-cholesterol and insulin sensitivity in healthy men with normal BMI compared to peanut oil. Clin Nutr. 2019. 38:2889-2899. doi:10.1016/j.clnu.2018.12.026 | Country
1148 | Koskinen, TT, Virtanen, HEK, Voutilainen, S, et al. Intake of fermented and nonfermented dairy products and risk of incident CHD: the Kuopio Ischaemic Heart Disease Risk Factor Study. Br J Nutr. 2018. 120:1288-1297. doi:10.1017/s0007114518002830 | Comparator
1149 | Kouguchi T, Ohmori T, Shimizu M, et al. Subgroup analysis of hypotensive effects of lactic acid bacteria beverage containing chicken collagen hydrolysate in subjects with high-normal blood pressure. Japan Pharmacology & Therapeutics. 2008;36(10):911-918. | Publication language
1150 | Kouki, R, Schwab, U, Hassinen, M, et al. Food consumption, nutrient intake and the risk of having metabolic syndrome: The DR’s EXTRA Study. European Journal of Clinical Nutrition. 2011. 65:368-377. doi:10.1038/ejcn.2010.262 | Study design; Outcome
1151 | Kourlaba, G, Polychronopoulos, E, Zampelas, A, et al. Development of a diet index for older adults and its relation to cardiovascular disease risk factors: the Elderly Dietary Index. J Am Diet Assoc. Jun 2009;109(6):1022-30. doi:10.1016/j.jada.2009.03.004 | Study design; Intervention/Exposure
1152 | Kouvari, M, Damigou, E, Florentin, M, et al. Egg Consumption, Cardiovascular Disease and Cardiometabolic Risk Factors: The Interaction with Saturated Fatty Acids. Results from the ATTICA Cohort Study (2002-2012). Nutrients. Dec 12 2022;14(24)doi:10.3390/nu14245291 | Intervention/Exposure
1153 | Kouvari, M, Panagiotakos, DB, Chrysohoou, C, et al. Dairy products, surrogate markers, and cardiovascular disease; a sex-specific analysis from the ATTICA prospective study. Nutr Metab Cardiovasc Dis. 2020. 30:2194-2206. doi:10.1016/j.numecd.2020.07.037 | Comparator
1154 | Kouvari, M, Panagiotakos, DB, Chrysohoou, C, et al. Meat consumption, depressive symptomatology and cardiovascular disease incidence in apparently healthy men and women: highlights from the ATTICA cohort study (2002-2012). Nutr Neurosci. Feb 2022;25(2):266-275. doi:10.1080/1028415X.2020.1750169 | Study design; Intervention/Exposure
1155 | Kouvari, M, Tsiampalis, T, Chrysohoou, C, et al. A Mediterranean diet microsimulation modeling in relation to cardiovascular disease burden: the ATTICA and GREECS epidemiological studies. Eur J Clin Nutr. 2022. 76:434-441. doi:10.1038/s41430-021-00967-6 | Study design
1156 | Kozima, Y, Urano, T, Serizawa, K, et al. Impaired fibrinolytic activity induced by ingestion of butter: effect of increased plasma lipids on the fibrinolytic activity. Thromb Res. 1993. 70:191-202. doi:10.1016/0049-3848(93)90159-l | Duration
1157 | Kozłowska-Wojciechowska M, Bukowska H, Makarewicz-Wujec M, Daniewski M, Naruszewicz M. Redukcja stezenia frakcji LDL-cholesterolu w surowicy młodych zdrowych mezczyzn w wyniku zamiany masła na margaryne miekka w zwyczajowej diecie [Reduction of the plasma LDL-cholesterol level among young healthy men as a result of the change from butter to soft margarine in the unbalanced diet]. Pol Arch Med Wewn. 2001;105(1):29-37. | Publication language
1158 | Kozłowska-Wojciechowska M, Milo B, Makarewicz-Wujec M, Chełstowski K, Naruszewicz M. Wpływ diety wzbogaconej w sterole roślinne na poziom lipidów i oksydowanych LDL u młodych mezczyzn [The impact of plant-sterol supplemented diet on the LDL and oxidized-LDL levels in young men]. Pol Arch Med Wewn. 2003;109(6):589-595. | Intervention/Exposure; Comparator
1159 | Kozłowska-Wojciechowska, M, Milo, B, Makarewicz-Wujec, M, et al. The impact of plant-sterol supplemented diet on the LDL and oxidized-LDL levels in young men. Pol Arch Med Wewn. 2003;109(6):589-595. | Publication language
1160 | Králíková E, Ceska R, Rames J. Diet, smoking, and blood lipids in patients with combined familial hyperlipidaemia. Cent Eur J Public Health. 1999;7(1):19-23. | Study design; Intervention/Exposure
1161 | Králová Lesná, I, Suchánek, P, Brabcová, E, et al. Effect of different types of dietary fatty acids on subclinical inflammation in humans. Physiol Res. 2013. 62:145-52. doi:10.33549/physiolres.932439 | Sample size/Power
1162 | Kralova Lesna, I, Suchanek, P, Kovar, J, et al. Replacement of dietary saturated FAs by PUFAs in diet and reverse cholesterol transport. J Lipid Res. 2008. 49:2414-8. doi:10.1194/jlr.M800271-JLR200 | Intervention/Exposure; Sample size/Power
1163 | Krauss, RM, Blanche, PJ, Rawlings, RS, et al. Separate effects of reduced carbohydrate intake and weight loss on atherogenic dyslipidemia. Am J Clin Nutr. May 2006;83(5):1025-31; quiz 1205. doi:10.1093/ajcn/83.5.1025 | Intervention/Exposure
1164 | Krauss, RM, Dreon, DM. Low-density-lipoprotein subclasses and response to a lowfat diet in healthy men. Am J Clin Nutr. Aug 1995;62(2):478S-487S. doi:10.1093/ajcn/62.2.478S | Intervention/Exposure
1165 | Krebs, JD, Evans, S, Cooney, L, et al. Changes in risk factors for cardiovascular disease with body fat loss in obese women. Diabetes Obes Metab. Nov 2002;4(6):379-87. doi:10.1046/j.1463-1326.2002.00231.x | Study design; Intervention/Exposure
1166 | Kreijkamp-Kaspers, S, Kok, L, Bots, ML, et al. Randomized controlled trial of the effects of soy protein containing isoflavones on vascular function in postmenopausal women. Am J Clin Nutr. 2005. 81:189-95. doi:10.1093/ajcn/81.1.189 | Intervention/Exposure
1167 | Krieger, JP, Cabaset, S, Pestoni, G, et al. Dietary Patterns Are Associated with Cardiovascular and Cancer Mortality among Swiss Adults in a Census-Linked Cohort. Nutrients. 2018. 10:313. doi:10.3390/nu10030313 | Intervention/Exposure
1168 | Kriengsinyos, W, Sumriddetchkajorn, K, Yamborisut, U. Reduction of LDL-cholesterol in mildly hypercholesterolemic Thais with plant stanol ester-fortified soy milk. J Med Assoc Thai. Nov 2011;94(11):1327-36. | Intervention/Exposure; Comparator
1169 | Krijger, JA, Nicolaou, M, Nguyen, AN, et al. Diet quality at age 5-6 and cardiovascular outcomes in preadolescents. Clinical Nutrition Espen. Jun 2021;43:506-513. doi:10.1016/j.clnesp.2021.02.011 | Intervention/Exposure
1170 | Kris-Etherton, PM, Derr, J, Mitchell, DC, et al. The role of fatty acid saturation on plasma lipids, lipoproteins, and apolipoproteins: I. Effects of whole food diets high in cocoa butter, olive oil, soybean oil, dairy butter, and milk chocolate on the plasma lipids of young men. Metabolism. 1993. 42:121-9. doi:10.1016/0026-0495(93)90182-n | Duration; Sample size/Power
1171 | Kris-Etherton, PM, Derr, JA, Mustad, VA, et al. Effects of a milk chocolate bar per day substituted for a high-carbohydrate snack in young men on an NCEP/AHA Step 1 Diet. Am J Clin Nutr. Dec 1994;60(6 Suppl):1037S-1042S. doi:10.1093/ajcn/60.6.1037S | Duration
1172 | Kris-Etherton, PM, Mustad, VA. Chocolate feeding studies: a novel approach for evaluating the plasma lipid effects of stearic acid. Am J Clin Nutr. Dec 1994;60(6 Suppl):1029S-1036S. doi:10.1093/ajcn/60.6.1029S | Study design; Intervention/Exposure
1173 | Kris-Etherton, PM, Pearson, TA, Wan, Y, et al. High-monounsaturated fatty acid diets lower both plasma cholesterol and triacylglycerol concentrations. American Journal of Clinical Nutrition. Dec 1999;70(6):1009-1015 | Duration; Sample size/Power
1174 | Kris-Etherton, PM, Petersen, K, Van Horn, L. Convincing evidence supports reducing saturated fat to decrease cardiovascular disease risk. BMJ Nutr Prev Health. 2018. 1:23-26. doi:10.1136/bmjnph-2018-000009 | Study design
1175 | Kris-Etherton, PM, Stewart, PW, Ginsberg, HN, et al. The Type and Amount of Dietary Fat Affect Plasma Factor VIIc, Fibrinogen, and PAI-1 in Healthy Individuals and Individuals at High Cardiovascular Disease Risk: 2 Randomized Controlled Trials. Journal of Nutrition. Aug 2020;150(8):2089-2100. doi:10.1093/jn/nxaa137 | Intervention/Exposure
1176 | Krishnan, S, Adams, SH, Witbracht, MG, et al. Weight Loss, but Not Dairy Composition of Diet, Moderately Affects Satiety and Postprandial Gut Hormone Patterns in Adults. Journal of Nutrition. 2021. 151:245-254. doi:10.1093/jn/nxaa327 | Intervention/Exposure; Outcome
1177 | Krishnan, S, O’Connor, LE, Wang, Y, et al. Adopting a Mediterranean-style eating pattern with low, but not moderate, unprocessed, lean red meat intake reduces fasting serum trimethylamine N-oxide (TMAO) in adults who are overweight or obese. British Journal of Nutrition. 2022. 128:1738-1746. doi:10.1017/S0007114521004694 | Outcome
1178 | Kruger, M, Mazahery, H, Mugridge, O, et al. A Comparative Randomized Intervention Trial of the Efficacy of Deer Milk and an Oral Nutritional Supplement for Improving Nutritional Status, Muscle Mass and Physical Performance in Older Adults. Aging Clinical and Experimental Research. Jul 2023;35:S263-S263. | Intervention/Exposure; Comparator
1179 | Kulezic, A, Bergwall, S, Fatemi, S, et al. Healthy diet and fiber intake are associated with decreased risk of incident symptomatic peripheral artery disease - A prospective cohort study. Vasc Med. Dec 2019;24(6):511-518. doi:10.1177/1358863X19867393 | Intervention/Exposure
1180 | Kuller, LH, Simkin-Silverman, LR, Wing, RR, et al. Women’s Healthy Lifestyle Project: A randomized clinical trial - Results at 54 months. Circulation. Jan 2 2001;103(1):32-37. | Intervention/Exposure
1181 | Kumagai, S, Shibata, H, Watanabe, S, et al. Effect of food intake pattern on all-cause mortality in the community elderly: a 7-year longitudinal study. J Nutr Health Aging. 1999;3(1):29-33. | Intervention/Exposure
1182 | Kunces, LJ, Cusack, LK, Kupchak, BR, et al. Triglyceride Recrystallized Phytosterols in Fat-Free Milk Improve Lipoprotein Profiles More Than Unmodified Free Phytosterols in Hypercholesterolemic Men and Women. Journal of the American College of Nutrition. Aug 1 2013;32(4):234-242. doi:10.1080/07315724.2013.816597 | Sample size/Power
1183 | Kurl, S, Laukkanen, JA, Niskanen, L, et al. Metabolic syndrome and the risk of stroke in middle-aged men. Stroke. Mar 2006;37(3):806-11. doi:10.1161/01.STR.0000204354.06965.44 | Intervention/Exposure
1184 | Kurmaeva, D, Ye, Y, Bakhytkyzy, I, et al. Associations between sheep meat intake frequency and blood plasma levels of metabolites and lipoproteins in healthy Uzbek adults. Metabolomics. Apr 26 2023;19(5)doi:ARTN 46 10.1007/s11306-023-02005-x | Study design
1185 | Kurniawan, AL, Hsu, CY, Lee, HA, et al. Comparing two methods for deriving dietary patterns associated with risk of metabolic syndrome among middle-aged and elderly Taiwanese adults with impaired kidney function. BMC Med Res Methodol. 2020. 20:255. doi:10.1186/s12874-020-01142-4 | Intervention/Exposure; Health status
1186 | Kurotani, K, Nanri, A, Goto, A, et al. Red meat consumption is associated with the risk of type 2 diabetes in men but not in women: a Japan Public Health Center-based Prospective Study. Br J Nutr. 2013. 110:1910-8. doi:10.1017/s0007114513001128 | Outcome
1187 | Kurth, T, Moore, SC, Gaziano, JM, et al. Healthy lifestyle and the risk of stroke in women. Arch Intern Med. Jul 10 2006;166(13):1403-9. doi:10.1001/archinte.166.13.1403 | Intervention/Exposure
1188 | Kwiterovich Jr, PO, Barton, BA, McMahon, RP, et al. Effects of diet and sexual maturation on low-density lipoprotein cholesterol during puberty: the Dietary Intervention Study in Children (DISC). Circulation. Oct 21 1997;96(8):2526-33. doi:10.1161/01.cir.96.8.2526 | Intervention/Exposure
1189 | Kwiterovich PO, Hartmuller G, Van Horn L, et al. Efficacy and Safety of Lowering Dietary Intake of Fat and Cholesterol in Children With Elevated Low-Density Lipoprotein Cholesterol: The Dietary Intervention Study in Children (DISC). JAMA. 1995;273(18):1429–1435. doi:10.1001/jama.1995.03520420045036 | Intervention/Exposure
1190 | Kwon, JS, Snook, JT, Wardlaw, GM, et al. Effects of diets high in saturated fatty acids, canola oil, or safflower oil on platelet function, thromboxane B2 formation, and fatty acid composition of platelet phospholipids. Am J Clin Nutr. Aug 1991;54(2):351-8. doi:10.1093/ajcn/54.2.351 | Intervention/Exposure; Comparator
1191 | Kwon, YJ, Hyun, DS, Koh, SB, et al. Differential relationship between dietary fat and cholesterol on total mortality in Korean population cohorts. Journal of Internal Medicine. Oct 2021;290(4):866-877. doi:10.1111/joim.13328 | Intervention/Exposure
1192 | Kwon, YJ, Lee, HS, Chang, HJ, et al. Association of dietary lipid intake with low-density lipoprotein cholesterol levels: analysis of two independent population-based studies. Eur J Nutr. 2020. 59:2557-2567. doi:10.1007/s00394-019-02104-3 | Study design
1193 | Kynast-Gales, SA, Massey, LK. Effects of dietary calcium from dairy products on ambulatory blood pressure in hypertensive men. J Am Diet Assoc. Dec 1992;92(12):1497-501. | Sample size/Power
1194 | L Sellem, B Srour, G Javaux, E Chazelas, B Chassaing, E Viennois, et al. Food additive emulsifiers and risk of cardiovascular disease in the NutriNet-Sante cohort: prospective cohort study. BMJ. Sep 6 2023;382:e076058. doi:10.1136/bmj-2023-076058 | Intervention/Exposure
1195 | Laake, I, Pedersen, JI, Selmer, R, et al. A prospective study of intake of trans-fatty acids from ruminant fat, partially hydrogenated vegetable oils, and marine oils and mortality from CVD. Br J Nutr. Aug 2012;108(4):743-54. doi:10.1017/S0007114511005897 | Intervention/Exposure
1196 | Laaksonen, DE, Lakka, TA, Lakka, HM, et al. Serum fatty acid composition predicts development of impaired fasting glycaemia and diabetes in middle-aged men. Diabet Med. 2002. 19:456-64. doi:10.1046/j.1464-5491.2002.00707.x | Intervention/Exposure
1197 | Laaksonen, DE, Nyyssönen, K, Niskanen, L, et al. Prediction of cardiovascular mortality in middle-aged men by dietary and serum linoleic and polyunsaturated fatty acids. Arch Intern Med. 2005. 165:193-9. doi:10.1001/archinte.165.2.193 | Intervention/Exposure
1198 | Laamanen SE, Eloranta AM, Haapala EA, Sallinen T, Schwab U, Lakka TA. Associations of diet quality and food consumption with serum biomarkers for lipid and amino acid metabolism in Finnish children: the PANIC study. Eur J Nutr. 2024;63(2):623-637. doi:10.1007/s00394-023-03293-8 | Study design
1199 | Labat, JB, Martini, MC, Carr, TP, et al. Cholesterol-lowering effects of modified animal fats in postmenopausal women. J Am Coll Nutr. Dec 1997;16(6):570-7 | Sample size/Power
1200 | Lacroix, E, Charest, A, Cyr, A, et al. Randomized controlled study of the effect of a butter naturally enriched in trans fatty acids on blood lipids in healthy women. Am J Clin Nutr. 2012. 95:318-25. doi:10.3945/ajcn.111.023408 | Comparator
1201 | Ladeia, AM, Costa-Matos, E, Barata-Passos, R, et al. A palm oil-rich diet may reduce serum lipids in healthy young individuals. Nutrition. Jan 2008;24(1):11-5. doi:10.1016/j.nut.2007.08.013 | Duration; Sample size/Power
1202 | Lafrenière, J, Carbonneau, E, Laramée, C, et al. Is the Canadian healthy eating index 2007 an appropriate diet indicator of metabolic health? insights from dietary pattern analysis in the PREDISE study. Article. Nutrients. 2019;11(7) | Intervention/Exposure
1203 | Lagiou, P, Sandin, S, Weiderpass, E, et al. Low carbohydrate-high protein diet and mortality in a cohort of Swedish women. J Intern Med. Apr 2007;261(4):366-74. doi:10.1111/j.1365-2796.2007.01774.x | Intervention/Exposure
1204 | Lagström, H, Seppänen, R, Jokinen, E, et al. Nutrient intakes and cholesterol values of the parents in a prospective randomized child-targeted coronary heart disease risk factor intervention trial-the STRIP project. Eur J Clin Nutr. Aug 1999;53(8):654-61. doi:10.1038/sj.ejcn.1600828 | Study design; No confounder adjustment; Population
1205 | Laguzzi, F, Maitusong, B, Strawbridge, RJ, et al. Intake of food rich in saturated fat in relation to subclinical atherosclerosis and potential modulating effects from single genetic variants. Sci Rep. 2021. 11:7866. doi:10.1038/s41598-021-86324-w | Intervention/Exposure
1206 | Lahoz, C, Alonso, R, Ordovás, JM, et al. Effects of dietary fat saturation on eicosanoid production, platelet aggregation and blood pressure. Eur J Clin Invest. Sep 1997;27(9):780-7. doi:10.1046/j.1365-2362.1997.1860735.x | Intervention/Exposure
1207 | Laitinen, TT, Nuotio, J, Niinikoski, H, et al. Attainment of Targets of the 20-Year Infancy-Onset Dietary Intervention and Blood Pressure Across Childhood and Young Adulthood: The Special Turku Coronary Risk Factor Intervention Project (STRIP). Hypertension. Nov 2020;76(5):1572-1579. | Intervention/Exposure
1208 | Lajous, M, Bijon, A, Fagherazzi, G, et al. Processed and unprocessed red meat consumption and hypertension in women. Am J Clin Nutr. 2014. 100:948-52. doi:10.3945/ajcn.113.080598 | Comparator
1209 | Lamarche, B, Desroches, S, Jenkins, DJ, et al. Combined effects of a dietary portfolio of plant sterols, vegetable protein, viscous fibre and almonds on LDL particle size. Br J Nutr. Oct 2004;92(4):657-63. doi:10.1079/bjn20041241 | Intervention/Exposure; Sample size/Power
1210 | Lamarche, B. Dietary sources of saturated fat may influence cardiovascular disease risk. Can Nurse. Mar 2013;109(3):19. | Study design; Publication status
1211 | Lambert, EA, Phillips, S, Belski, R, et al. Endothelial Function in Healthy Young Individuals Is Associated with Dietary Consumption of Saturated Fat. Front Physiol. 2017. 8:876. doi:10.3389/fphys.2017.00876 | Intervention/Exposure; Duration
1212 | Lamichhane, AP, Liese, AD, Urbina, EM, et al. Associations of dietary intake patterns identified using reduced rank regression with markers of arterial stiffness among youth with type 1 diabetes. Eur J Clin Nutr. 2014. 68:1327-33. doi:10.1038/ejcn.2014.96 | Health status
1213 | Lana, A, Banegas, JR, Guallar-Castillón, P, et al. Association of Dairy Consumption and 24-Hour Blood Pressure in Older Adults with Hypertension. Am J Med. Oct 2018;131(10):1238-1249. doi:10.1016/j.amjmed.2018.04.039 | Study design
1214 | Lana, A, Rodriguez-Artalejo, F, Lopez-Garcia, E. Dairy Consumption and Risk of Frailty in Older Adults: A Prospective Cohort Study. J Am Geriatr Soc. Sep 2015;63(9):1852-60. doi:10.1111/jgs.13626 | Outcome
1215 | Lancaster, KJ, Smiciklas-Wright, H, Weitzel, LB, et al. Hypertension-related dietary patterns of rural older adults. Prev Med. 2004. 38:812-8. doi:10.1016/j.ypmed.2004.01.002 | Study design; Outcome
1216 | Landi F, Calvani R, Martone AM, et al. Daily meat consumption and variation with aging in community-dwellers: Results from longevity check-up 7 + project. Journal of Gerontology and Geriatrics. 2019;67:62-66. | Study design; Intervention/Exposure
1217 | Langsetmo, L, Harrison, S, Jonnalagadda, S, et al. Low Protein Intake Irrespective of Source is Associated with Higher Mortality Among Older Community-Dwelling Men. Journal of Nutrition Health & Aging. Aug 2020;24(8):900-905. doi:10.1007/s12603-0201422-4 | Intervention/Exposure
1218 | Lankinen, M, Schwab, U, Kolehmainen, M, et al. A Healthy Nordic Diet Alters the Plasma Lipidomic Profile in Adults with Features of Metabolic Syndrome in a Multicenter Randomized Dietary Intervention. J Nutr. Apr 1 2015;146(4):662-672. doi:10.3945/jn.115.220459 | Intervention/Exposure
1219 | Lara, JJ, Economou, M, Wallace, AM, et al. Benefits of salmon eating on traditional and novel vascular risk factors in young, non-obese healthy subjects. Atherosclerosis. Jul 2007;193(1):213-21. doi:10.1016/j.atherosclerosis.2006.06.018 | Intervention/Exposure
1220 | Larson EA, Magkos F, Zingenberg H, Svare J, Astrup A, Geiker NRW. A high protein low glycemic index diet has no adverse effect on blood pressure in pregnant women with overweight or obesity: a secondary data analysis of a randomized clinical trial. Front Nutr. 2023;10:1289395. Published 2023 Nov 21. doi:10.3389/fnut.2023.1289395 | Intervention/Exposure
1221 | Larsson, SC, . Primary prevention of stroke by a healthy lifestyle in a high-risk group. Neurology. 2015. 84:2224-8. doi:10.1212/wnl.0000000000001637 | Intervention/Exposure
1222 | Larsson, SC, Drca, N, Jensen-Urstad, M, et al. Chocolate consumption and risk of atrial fibrillation: Two cohort studies and a meta-analysis. American Heart Journal. 2018. 195:86-90. doi:10.1016/j.ahj.2017.09.013 | Outcome
1223 | Larsson, SC, Männistö, S, Virtanen, MJ, et al. Dairy foods and risk of stroke. Epidemiology. 2009. 20:355-60. doi:10.1097/EDE.0b013e3181935dd5 | Comparator
1224 | Larsson, SC, Virtamo, J, Wolk, A. Dairy consumption and risk of stroke in Swedish women and men. Stroke. Jul 2012;43(7):1775-80. doi:10.1161/STROKEAHA.111.641944 | Comparator
1225 | Larsson, SC, Virtamo, J, Wolk, A. Dietary fats and dietary cholesterol and risk of stroke in women. Atherosclerosis. Mar 2012;221(1):282-6. doi:10.1016/j.atherosclerosis.2011.12.043 | Intervention/Exposure
1226 | Larsson, SC, Virtamo, J, Wolk, A. Red meat consumption and risk of stroke in Swedish men. Am J Clin Nutr. 2011. 94:417-21. doi:10.3945/ajcn.111.015115 | Comparator
1227 | Larsson, SC, Virtamo, J, Wolk, A. Red meat consumption and risk of stroke in Swedish women. Stroke. Feb 2011;42(2):324-9. doi:10.1161/STROKEAHA.110.596510 | Comparator
1228 | Larsson, SC, Wallin, A, Wolk, A. Dietary Approaches to Stop Hypertension Diet and Incidence of Stroke: Results From 2 Prospective Cohorts. Stroke. Apr 2016;47(4):986-90. doi:10.1161/STROKEAHA.116.012675 | Intervention/Exposure
1229 | Larsson, SC, Wolk, A, Bäck, M. Dietary patterns, food groups, and incidence of aortic valve stenosis: A prospective cohort study. Int J Cardiol. 2019. 283:184-188. doi:10.1016/j.ijcard.2018.11.007 | Outcome
1230 | Larsson, SC, Wolk, K, Brismar, K, et al. Association of diet with serum insulin-like growth factor I in middle-aged and elderly men. Am J Clin Nutr. 2005. 81:1163-7. doi:10.1093/ajcn/81.5.1163 | Outcome
1231 | Lauer, RM, Obarzanek, E, Hunsberger, SA, et al. Efficacy and safety of lowering dietary intake of total fat, saturated fat, and cholesterol in children with elevated LDL cholesterol: the Dietary Intervention Study in Children. Am J Clin Nutr. Nov 2000;72(5 Suppl):1332S-1342S. doi:10.1093/ajcn/72.5.1332s | Intervention/Exposure
1232 | Laurin, D, Jacques, H, Moorjani, S, et al. Effects of a soy-protein beverage on plasma lipoproteins in children with familial hypercholesterolemia. Am J Clin Nutr. Jul 1991;54(1):98-103. doi:10.1093/ajcn/54.1.98 | Sample size/Power
1233 | Laursen, ASD, Dahm, CC, Johnsen, SP, et al. Adipose tissue fatty acids present in dairy fat and risk of stroke: the Danish Diet, Cancer and Health cohort. Eur J Nutr. Mar 2019;58(2):529-539. doi:10.1007/s00394-018-1608-2 | Intervention/Exposure
1234 | Lavigne JV, Brown KM, Gidding S, et al. A cholesterol-lowering diet does not produce adverse psychological effects in children: three-year results from the dietary intervention study in children. Health Psychol. 1999;18(6):604-613. doi:10.1037//0278-6133.18.6.604 | Intervention/Exposure
1235 | Law, HG, Khan, MA, Zhang, W, et al. Reducing saturated fat intake lowers LDL-C but increases Lp(a) levels in African Americans: the GET-READI feeding trial. J Lipid Res. Sep 2023;64(9):100420. doi:10.1016/j.jlr.2023.100420 | Intervention/Exposure
1236 | Lawlor D. Dietary saturated fats may not be harmful in the absence of other risk factors. Int J Epidemiol. 2002;31(1):282. | Study design; Publication status
1237 | Lawlor, DA, Ebrahim, S, Timpson, N, et al. Avoiding milk is associated with a reduced risk of insulin resistance and the metabolic syndrome: findings from the British Women’s Heart and Health Study. Diabetic Medicine. Jun 2005;22(6):808-811. doi:DOI 10.1111/j.1464-5491.2005.01537.x | Study design
1238 | Lawton, CL. Regulation of energy and fat intakes and body weight: the role of fat substitutes. Br J Nutr. 1998. 80:3-4. doi:10.1017/s0007114598001706 | Study design
1239 | Lazarova, SV, Jessri, M. Associations between dietary patterns and cardiovascular disease risk in Canadian adults: a comparison of partial least squares, reduced rank regression, and the simplified dietary pattern technique. Am J Clin Nutr. 2022. 116:362-377. doi:10.1093/ajcn/nqac117 | Intervention/Exposure
1240 | Le, T, Flatt, SW, Natarajan, L, et al. Effects of Diet Composition and Insulin Resistance Status on Plasma Lipid Levels in a Weight Loss Intervention in Women. J Am Heart Assoc. 2016. 5:e002771. doi:10.1161/jaha.115.002771 | Intervention/Exposure
1241 | Leary, MP, Lim, J, Park, W, et al. Non-fat milk attenuates acute hypertriglyceridemia in obese individuals who consume a high fat diet: a randomized control trial. Journal of nutrition and intermediary metabolism. 2018. 12:8-13. doi:10.1016/j.jnim.2018.05.003 | Duration
1242 | Leblanc, V, Bégin, C, Hudon, AM, et al. Gender differences in the long-term effects of a nutritional intervention program promoting the Mediterranean diet: changes in dietary intakes, eating behaviors, anthropometric and metabolic variables. Nutr J. 2014. 13:107. doi:10.1186/1475-2891-13-107 | Intervention/Exposure
1243 | Leblanc, V, Hudon, AM, Royer, MM, et al. Differences between men and women in dietary intakes and metabolic profile in response to a 12-week nutritional intervention promoting the Mediterranean diet. J Nutr Sci. 2015. 4:e13. doi:10.1017/jns.2015.2 | Intervention/Exposure
1244 | Lecerf, JM, Luc, G, Marécaux, N, et al. Small, qualitative changes in fatty acid intake decrease plasma low-density lipoprotein-cholesterol levels in mildly hypercholesterolemic outpatients on their usual high-fat diets. International Journal of Food Sciences and Nutrition. 2009;60:151-163. doi:10.1080/09637480902758727 | Intervention/Exposure; Comparator
1245 | Leddy, J, Horvath, P, Rowland, J, et al. Effect of a high or a low fat diet on cardiovascular risk factors in male and female runners. Med Sci Sports Exerc. Jan 1997;29(1):17-25. doi:10.1097/00005768-199701000-00004 | Intervention/Exposure; Sample size/Power
1246 | Lederer, AK, Storz, MA, Huber, R, et al. Plasma Leptin and Adiponectin after a 4-Week Vegan Diet: A Randomized-Controlled Pilot Trial in Healthy Participants. Int J Environ Res Public Health. Sep 9 2022;19(18)doi:10.3390/ijerph191811370 | Outcome; Sample size/Power
1247 | Lee YJ, Seo JA, Yoon T, et al. Effects of low-fat milk consumption on metabolic and atherogenic biomarkers in Korean adults with the metabolic syndrome: a randomised controlled trial. J Hum Nutr Diet. 2016;29(4):477-486. doi:10.1111/jhn.12349 | Sample size/Power
1248 | Lee, HA, An, H, Lee, E. Dietary patterns related to cardiovascular disease based on reduced rank regression analysis of healthy middle-aged Koreans: data from the community-based Korean Genome and Epidemiology Study (KoGES) cohort. Am J Clin Nutr. 2020. 111:1159-1169. doi:10.1093/ajcn/nqaa078 | Intervention/Exposure
1249 | Lee, HA, An, H, Park, H. Identification of Dietary Patterns Related to Metabolic Diseases and Their Association with Cardiovascular Disease: From the Korean Genome and Epidemiology Study. Nutrients. Oct 12 2019;11(10)doi:10.3390/nu11102434 | Intervention/Exposure
1250 | Lee, HA, An, H. The Effect of High Carbohydrate-to-fat Intake Ratios on Hypo-HDL-cholesterolemia Risk and HDL-cholesterol Levels over a 12-year Follow-up. Sci Rep. 2020. 10:913. doi:10.1038/s41598-020-57931-w | Intervention/Exposure
1251 | Lee, HA, Park, H. Diet-Related Risk Factors for Incident Hypertension During an 11-Year Follow-Up: The Korean Genome Epidemiology Study. Nutrients. Aug 13 2018;10(8)doi:10.3390/nu10081077 | Comparator
1252 | Lee, J, Kim, J Association between Dietary Pattern and Incidence of Cholesterolemia in Korean Adults: The Korean Genome and Epidemiology Study. Nutrients. Jan 9 2018;10(1)doi:10.3390/nu10010053 | Intervention/Exposure
1253 | Lee, JE, McLerran, DF, Rolland, B, et al. Meat intake and cause-specific mortality: a pooled analysis of Asian prospective cohort studies. Am J Clin Nutr. 2013. 98:1032-41. doi:10.3945/ajcn.113.062638 | Study design
1254 | Lee, J-E. Effect of Health-Related Behavior and Nutrition Intake on the Blood Lipids Levels. Article. Current Research in Nutrition and Food Science. Apr 2023;11(1):210-222. doi:10.12944/Crnfsj.11.1.15 | Intervention/Exposure
1255 | Lee, KW, Cho, W. The consumption of dairy products is associated with reduced risks of obesity and metabolic syndrome in Korean women but not in men. Nutrients. 2017. 9:630. doi:10.3390/nu9060630 | Study design
1256 | Lee, KW, Shin, D. A Healthy Beverage Consumption Pattern Is Inversely Associated with the Risk of Obesity and Metabolic Abnormalities in Korean Adults. J Med Food. 2018. 21:935-945. doi:10.1089/jmf.2017.0119 | Study design; Intervention/Exposure
1257 | Lee, KW, Woo, HD, Cho, MJ, et al. Identification of Dietary Patterns Associated with Incidence of Hyperglycemia in Middle-Aged and Older Korean Adults. Article. Nutrients. Aug 4 2019;11(8)doi:10.3390/nu11081801 | Intervention/Exposure
1258 | Lee, R, Balick, M. Rx: chocolate. Explore (NY). Mar 2005;1(2):136-9. doi:10.1016/j.explore.2004.12.011 | Study design; Publication status
1259 | Lee, S, Harnack, L, Jacobs, DR, et al. Trends in diet quality for coronary heart disease prevention between 1980-1982 and 2000-2002: The Minnesota Heart Survey. Journal of the American Dietetic Association. Feb 2007;107(2):213-222. doi:10.1016/j.jada.2006.11.003 | Study design; Intervention/Exposure
1260 | Lee, SPS, Dart, AM, Walker, KZ, et al. Effect of altering dietary n-6:n-3 PUFA ratio on cardiovascular risk measures in patients treated with statins: A pilot study. British Journal of Nutrition. 2012. 108:1280-1285. doi:10.1017/S0007114511006519 | Intervention/Exposure
1261 | Lee, YJ, Song, S, Song, Y. High-Carbohydrate Diets and Food Patterns and Their Associations with Metabolic Disease in the Korean Population. Yonsei Med J. 2018. 59:834-842. doi:10.3349/ymj.2018.59.7.834 | Study design
1262 | Lee, YM, Skurk, T, Hennig, M, et al. Effect of a milk drink supplemented with whey peptides on blood pressure in patients with mild hypertension. Eur J Nutr. 2007. 46:21-7. doi:10.1007/s00394-006-0625-8 | Intervention/Exposure; Comparator
1263 | Leeds, A. Dietary factors in heart disease. Nurs Stand. Aug 7-13 1991;5(46):26-8. doi:10.7748/ns.5.46.26.s37 | Study design
1264 | Lefevre, M, Champagne, CM, Tulley, RT, et al. Individual variability in cardiovascular disease risk factor responses to low-fat and low-saturated-fat diets in men: body mass index, adiposity, and insulin resistance predict changes in LDL cholesterol. Am J Clin Nutr. 2005. 82:957-63; quiz 1145-6. doi:10.1093/ajcn/82.5.957 | Intervention/Exposure
1265 | Lehtovirta, M, Pahkala, K, Niinikoski, H, et al. Effect of Dietary Counseling on a Comprehensive Metabolic Profile from Childhood to Adulthood. J Pediatr. Apr 2018;195:190-198 e3. doi:10.1016/j.jpeds.2017.11.057 | Intervention/Exposure
1266 | Leite, ML, Nicolosi, A. Dietary patterns and metabolic syndrome factors in a non-diabetic Italian population. Public Health Nutr. 2009. 12:1494-503. doi:10.1017/s1368980008004539 | Study design; Intervention/Exposure
1267 | Lelong, H, Blacher, J, Baudry, J, et al. Individual and Combined Effects of Dietary Factors on Risk of Incident Hypertension: Prospective Analysis From the NutriNet-Santé Cohort. Hypertension. 2017. 70:712-720. doi:10.1161/hypertensionaha.117.09622 | Comparator
1268 | Lemcke-Norojärvi, M, Kamal-Eldin, A, Appelqvist, LA, et al. Corn and sesame oils increase serum gamma-tocopherol concentrations in healthy Swedish women. J Nutr. Apr 2001;131(4):1195-201. doi:10.1093/jn/131.4.1195 | Intervention/Exposure; Sample size/Power
1269 | Lemos, BS, Medina-Vera, I, Blesso, CN, et al. Intake of 3 Eggs per Day When Compared to a Choline Bitartrate Supplement, Downregulates Cholesterol Synthesis without Changing the LDL/HDL Ratio. Nutrients. Feb 24 2018;10(2)doi:10.3390/nu10020258 | Intervention/Exposure
1270 | Leosdottir, M, Nilsson, PM, Nilsson, JA, et al. Cardiovascular event risk in relation to dietary fat intake in middle-aged individuals: data from The Malmo Diet and Cancer Study. Eur J Cardiovasc Prev Rehabil. Oct 2007;14(5):701-6. doi:10.1097/HJR.0b013e3282a56c45 | Intervention/Exposure
1271 | Leosdottir, M, Nilsson, PM, Nilsson, JA, et al. Dietary fat intake and early mortality patterns-data from The Malmo Diet and Cancer Study. J Intern Med. Aug 2005;258(2):153-65. doi:10.1111/j.1365-2796.2005.01520.x | Intervention/Exposure
1272 | Lerman-Garber, I, Ichazo-Cerro, S, Zamora-González, J, et al. Effect of a high-monounsaturated fat diet enriched with avocado in NIDDM patients. Diabetes Care. 1994. 17:311-5. doi:10.2337/diacare.17.4.311 | Intervention/Exposure; Health status
1273 | Leslie, WS, Lean, ME, Baillie, HM, et al. Weight management: a comparison of existing dietary approaches in a work-site setting. Int J Obes Relat Metab Disord. 2002. 26:1469-75. doi:10.1038/sj.ijo.0802153 | Intervention/Exposure
1274 | Lestiani, L, Chandra, DN, Laitinen, K, et al. Double-Blind Randomized Placebo Controlled Trial Demonstrating Serum Cholesterol Lowering Efficacy of a Smoothie Drink with Added Plant Stanol Esters in an Indonesian Population. Cholesterol. 2018. 2018:4857473. doi:10.1155/2018/4857473 | Intervention/Exposure; Comparator
1275 | Letois, F, Mura, T, Scali, J, et al. Nutrition and mortality in the elderly over 10 years of follow-up: the Three-City study. Br J Nutr. Sep 2016;116(5):882-9. doi:10.1017/S000711451600266X | Outcome
1276 | Lewis JI, Lind MV, Møller G, et al. The effect of traditional diet on glucose homoeostasis in carriers and non-carriers of a common TBC1D4 variant in Greenlandic Inuit: a randomised crossover study. Br J Nutr. 2023;130(11):1871-1884. doi:10.1017/S000711452300106X | Intervention/Exposure; Sample size/Power
1277 | Lewis JI, Lind MV, Møller G, et al. The effect of traditional diet on glucose homoeostasis in carriers and non-carriers of a common TBC1D4 variant in Greenlandic Inuit: a randomised crossover study. Br J Nutr. 2023;130(11):1871-1884. doi:10.1017/S000711452300106X | Intervention/Exposure
1278 | Leyva-Soto A, Chavez-Santoscoy RA, Lara-Jacobo LR, Chavez-Santoscoy AV, Gonzalez-Cobian LN. Daily Consumption of Chocolate Rich in Flavonoids Decreases Cellular Genotoxicity and Improves Biochemical Parameters of Lipid and Glucose Metabolism. Molecules. 2018;23(9):2220. Published 2018 Sep 1. doi:10.3390/molecules23092220 | Intervention/Exposure; Outcome
1279 | Li J, Lee DH, Hu J, et al. Dietary Inflammatory Potential and Risk of Cardiovascular Disease Among Men and Women in the U.S. J Am Coll Cardiol. 2020;76(19):2181-2193. doi:10.1016/j.jacc.2020.09.535 | Intervention/Exposure
1280 | Li, C, Li, Y, Wang, N, et al. The Increased Risk of Hypertension Caused by Irrational Dietary Pattern May Be Associated with Th17 Cell in the Middle-Aged and Elderly Rural Residents of Beijing City, Northern China: A 1:1 Matched Case-Control Study. Nutrients. Jan 6 2023;15(2)doi:10.3390/nu15020290 | Study design
1281 | Li, D, Mann, NJ, Sinclair, AJ. Comparison of n-3 polyunsaturated fatty acids from vegetable oils, meat, and fish in raising platelet eicosapentaenoic acid levels in humans. Lipids. 1999;34 Suppl:S309. doi:10.1007/BF02562327 | Study design; Publication status
1282 | Li, D. Relationship between the concentrations of plasma phospholipid stearic acid and plasma lipoprotein lipids in healthy men. Clinical Science. Jan 2001;100(1):25-32. doi:Doi 10.1042/Cs20000109 | Study design
1283 | Li, J, Armstrong, CL, Campbell, WW. Effects of Dietary Protein Source and Quantity during Weight Loss on Appetite, Energy Expenditure, and Cardio-Metabolic Responses. Nutrients. 2016. 8:63. doi:10.3390/nu8020063 | Sample size/Power
1284 | Li, J, Guasch-Ferré, M, Chung, W, et al. The Mediterranean diet, plasma metabolome, and cardiovascular disease risk. Eur Heart J. Jul 21 2020;41(28):2645-2656. doi:10.1093/eurheartj/ehaa209 | Intervention/Exposure
1285 | Li, KJ, Brouwer-Brolsma, EM, Fleuti, C, et al. Associations between dairy fat intake, milk-derived free fatty acids, and cardiometabolic risk in Dutch adults. Eur J Nutr. 2023. 62:185-198. doi:10.1007/s00394-022-02974-0 | Study design
1286 | Li, M, Shi, Z. Dietary Pattern during 1991-2011 and Its Association with Cardio Metabolic Risks in Chinese Adults: The China Health and Nutrition Survey. Nutrients. Nov 6 2017;9(11)doi:10.3390/nu9111218 | Country
1287 | Li, M, Shi, Z. Ultra-Processed Food Consumption Associated with Incident Hypertension among Chinese Adults-Results from China Health and Nutrition Survey 1997-2015. Article. Nutrients. Nov 2022;14(22)doi:ARTN 4783 10.3390/nu14224783 | Intervention/Exposure; Country
1288 | Li, P, Zhang, M, Zhu, Y, et al. Dietary patterns and changes in cardiovascular risk factors in apparently healthy Chinese women: a longitudinal study. J Clin Biochem Nutr. 2016. 58:232-9. doi:10.3164/jcbn.15-78 | Intervention/Exposure; Country
1289 | Li, S, Flint, A, Pai, JK, et al. Low Carbohydrate Diet From Plant or Animal Sources and Mortality Among Myocardial Infarction Survivors. Article. Journal of the American Heart Association. Oct 2014;3(5)doi:ARTN e001169 10.1161/JAHA.114.001169 | Health status
1290 | Li, TY, Brennan, AM, Wedick, NM, et al. Regular consumption of nuts is associated with a lower risk of cardiovascular disease in women with type 2 diabetes. J Nutr. 2009. 139:1333-8. doi:10.3945/jn.108.103622 | Intervention/Exposure; Health status
1291 | Li, X, Wu, C, Lu, J, et al. Cardiovascular risk factors in China: a nationwide population-based cohort study. Lancet Public Health. 2020. 5:e672-e681. doi:10.1016/s2468-2667(20)30191-2 | Intervention/Exposure; Outcome
1292 | Li, X, Yin, J, Zhu, Y, et al. Effects of Whole Milk Supplementation on Gut Microbiota and Cardiometabolic Biomarkers in Subjects with and without Lactose Malabsorption. Nutrients. Oct 2018;10(10)doi:ARTN 1403 10.3390/nu10101403 | Comparator
1293 | Li, Y, He, Y, Lai, J, et al. Dietary patterns are associated with stroke in Chinese adults. J Nutr. 2011. 141:1834-9. doi:10.3945/jn.111.143883 | Intervention/Exposure; Country
1294 | Li, Y, Hruby, A, Bernstein, AM, et al. Saturated Fats Compared With Unsaturated Fats and Sources of Carbohydrates in Relation to Risk of Coronary Heart Disease: A Prospective Cohort Study. J Am Coll Cardiol. Oct 6 2015;66(14):1538-1548. doi:10.1016/j.jacc.2015.07.055 | Intervention/Exposure
1295 | Li, Y, Yatsuya, H, Wang, C, et al. Dietary Patterns Derived from Reduced Rank Regression Are Associated with the 5-Year Occurrence of Metabolic Syndrome: Aichi Workers’ Cohort Study. Article. Nutrients. Jul 22 2022;14(15)doi:10.3390/nu14153019 | Intervention/Exposure
1296 | Li, Z, Lamon-Fava, S, Otvos, J, et al. Fish consumption shifts lipoprotein subfractions to a less atherogenic pattern in humans. J Nutr. 2004. 134:1724-8. doi:10.1093/jn/134.7.1724 | Intervention/Exposure
1297 | Lian, Z, Perrard, XD, Antony, AK, et al. Dietary Effects on Monocyte Phenotypes in Subjects With Hypertriglyceridemia and Metabolic Syndrome. JACC Basic Transl Sci. 2023. 8:460-475. doi:10.1016/j.jacbts.2023.02.011 | Intervention/Exposure; Duration
1298 | Liang, F, Young, J, Koutsidis, G, et al. The effects of extra virgin olive oil or butter on cardiovascular biomarkers in European and Chinese males in the UK: A pilot randomised crossover trial. Nutr Health. Jul 18 2023:2601060231187516. doi:10.1177/02601060231187516 | Duration
1299 | Liang, J, Zhao, JK, Wang, JP, et al. Association between animal source foods consumption and risk of hypertension: a cohort study. European Journal of Nutrition. Aug 2021;60(5):2469-2483. doi:10.1007/s00394-020-02423-w | Country
1300 | Liao, FH, Shieh, MJ, Yang, SC, et al. Effectiveness of a soy-based compared with a traditional low-calorie diet on weight loss and lipid levels in overweight adults. Nutrition. 2007. 23:551-6. doi:10.1016/j.nut.2007.05.003 | Intervention/Exposure; Sample size/Power
1301 | Liau, KM, Lee, YY, Chen, CK, et al. An open-label pilot study to assess the efficacy and safety of virgin coconut oil in reducing visceral adiposity. ISRN Pharmacol. 2011. 2011:949686. doi:10.5402/2011/949686 | Duration; Sample size/Power
1302 | Libby P, Pinkosky SL, Nissen SE. Conquering cholesterol: a report from the front lines. Cardiovasc Res. 2023;119(17):e160-e163. doi:10.1093/cvr/cvad152 | Study design
1303 | Lichert, F. Does a MedDairy intervention improve cardiovascular health?. Aktuel Ernahrungsmed. 2019. | Publication status; Publication language
1304 | Lichtenstein, AH, Ausman, LM, Carrasco, W, et al. Effects of Canola, Corn, and Olive Oils on Fasting and Postprandial Plasma-Lipoproteins in Humans as Part of a National Cholesterol Education-Program Step 2 Diet. Arteriosclerosis and Thrombosis. Oct 1993;13(10):1533-1542. doi:Doi 10.1161/01.Atv.13.10.1533 | Sample size/Power
1305 | Lichtenstein, AH, Ausman, LM, Carrasco, W, et al. Hydrogenation impairs the hypolipidemic effect of corn oil in humans. Hydrogenation, trans fatty acids, and plasma lipids. Arterioscler Thromb. Feb 1993;13(2):154-61. doi:10.1161/01.atv.13.2.154 | Intervention/Exposure; Sample size/Power
1306 | Lichtenstein, AH, Ausman, LM, Carrasco, W, et al. Hypercholesterolemic effect of dietary cholesterol in diets enriched in polyunsaturated and saturated fat. Dietary cholesterol, fat saturation, and plasma lipids. Arterioscler Thromb. Jan 1994;14(1):168-75. doi:10.1161/01.atv.14.1.168 | Sample size/Power
1307 | Lichtenstein, AH, Ausman, LM, Carrasco, W, et al. Rice bran oil consumption and plasma lipid levels in moderately hypercholesterolemic humans. Arterioscler Thromb. Apr 1994;14(4):549-56. doi:10.1161/01.atv.14.4.549 | Intervention/Exposure; Sample size/Power
1308 | Lichtenstein, AH, Ausman, LM, Carrasco, W, et al. Short-Term Consumption of a Low-Pat Diet Beneficially Affects Plasma-Lipid Concentrations Only When Accompanied by Weight-Loss - Hypercholesterolemia, Low-Fat Diet, and Plasma-Lipids. Arteriosclerosis and Thrombosis. Nov 1994;14(11):1751-1760. doi:Doi 10.1161/01.Atv.14.11.1751 | Intervention/Exposure; Sample size/Power
1309 | Lichtenstein, AH, Ausman, LM, Jalbert, SM, et al. Efficacy of a Therapeutic Lifestyle Change/Step 2 diet in moderately hypercholesterolemic middle-aged and elderly female and male subjects. J Lipid Res. Feb 2002;43(2):264-73. | Intervention/Exposure
1310 | Lichtenstein, AH, Erkkilä, AT, Lamarche, B, et al. Influence of hydrogenated fat and butter on CVD risk factors: remnant-like particles, glucose and insulin, blood pressure and C-reactive protein. Atherosclerosis. Nov 2003;171(1):97-107. doi:10.1016/j.atherosclerosis.2003.07.005 | Study design; Sample size/Power
1311 | Lichtenstein, AH, Jauhiainen, M, McGladdery, S, et al. Impact of hydrogenated fat on high density lipoprotein subfractions and metabolism. J Lipid Res. Apr 2001;42(4):597-604. | Data overlap
1312 | Lichtenstein, AH, Matthan, NR, Jalbert, SM, et al. Novel soybean oils with different fatty acid profiles alter cardiovascular disease risk factors in moderately hyperlipidemic subjects. Am J Clin Nutr. 2006. 84:497-504. doi:10.1093/ajcn/84.3.497 | Intervention/Exposure; Comparator
1313 | Liese, AD, Nichols, M, Hodo, D, et al. Food intake patterns associated with carotid artery atherosclerosis in the Insulin Resistance Atherosclerosis Study. Br J Nutr. May 2010;103(10):1471-9. doi:10.1017/S0007114509993369 | Intervention/Exposure
1314 | Liese, AD, Wambogo, E, Lerman, JL, et al. Variations in Dietary Patterns Defined by the Healthy Eating Index 2015 and Associations with Mortality: Findings from the Dietary Patterns Methods Project. J Nutr. 2022. 152:796-804. doi:10.1093/jn/nxab383 | Intervention/Exposure
1315 | Lim, GB. Coconut oil raises LDL-cholesterol levels. Nat Rev Cardiol. Apr 2020;17(4):200. doi:10.1038/s41569-020-0345-4 | Study design; Publication status
1316 | Lima, ST, da Silva Nalin de Souza, B, França, AK, et al. Dietary approach to hypertension based on low glycaemic index and principles of DASH (Dietary Approaches to Stop Hypertension): a randomised trial in a primary care service. Br J Nutr. Oct 2013;110(8):1472-9. doi:10.1017/S0007114513000718 | Intervention/Exposure
1317 | Lima, ST. Impact of nutritional intervention in the control of blood pressure and metabolic levels in hypertensive patients in primary health care in São Luís - MA. | Publication status
1318 | Lin, P, Chang, CC, Yuan, KC, et al. Red Blood Cell Aggregation-Associated Dietary Pattern Predicts Hyperlipidemia and Metabolic Syndrome. Nutrients. 2018. 10:1127. doi:10.3390/nu10081127 | Intervention/Exposure
1319 | Lin, P, Gui, X, Liang, Z, et al. Association of Yogurt and Dietary Supplements Containing Probiotic Consumption With All-Cause and Cause-Specific Mortality in US Adults: A Population-Based Cohort Study. Front Nutr. 2022. 9:803076. doi:10.3389/fnut.2022.803076 | Comparator
1320 | Lin, PH, Aickin, M, Champagne, C, et al. Food group sources of nutrients in the dietary patterns of the DASH-Sodium trial. J Am Diet Assoc. 2003. 103:488-96. doi:10.1053/jada.2003.50065 | Outcome
1321 | Lin, PH, Yeh, WT, Svetkey, LP, et al. Dietary intakes consistent with the DASH dietary pattern reduce blood pressure increase with age and risk for stroke in a Chinese population. Asia Pac J Clin Nutr. 2013;22(3):482-91. | Country
1322 | Lin, WT, Lee, CY, Tsai, S, et al. Clustering of Metabolic Risk Components and Associated Lifestyle Factors: A Nationwide Adolescent Study in Taiwan. Nutrients. Mar 9 2019;11(3)doi:10.3390/nu11030584 | Study design
1323 | Lindqvist, H, Langkilde, AM, Undeland, I, et al. Herring (Clupea harengus) supplemented diet influences risk factors for CVD in overweight subjects. Eur J Clin Nutr. 2007. 61:1106-13. doi:10.1038/sj.ejcn.1602630 | Sample size/Power
1324 | Lindström T, Kechagias S, Carlsson M, Nystrom FH; Fast Food Study Group. Transient increase in HDL-cholesterol during weight gain by hyperalimentation in healthy subjects. Obesity (Silver Spring). 2011;19(4):812-817. doi:10.1038/oby.2010.190 | Sample size/Power
1325 | Liou, YA, King, DJ, Zibrik, D, et al. Decreasing linoleic acid with constant alpha-linolenic acid in dietary fats increases (n-3) eicosapentaenoic acid in plasma phospholipids in healthy men. J Nutr. 2007. 137:945-52. doi:10.1093/jn/137.4.945 | Intervention/Exposure; Sample size/Power
1326 | Little, P, Girling, G, Hasler, A, et al. The effect of a combination low sodium, low fat, high fibre diet on serum lipids in treated hypertensive patients. Eur J Clin Nutr. Apr 1990;44(4):293-300. | Intervention/Exposure
1327 | Liu ZM, Ho SC, Chen YM, et al. Whole soy, but not purified daidzein, had a favorable effect on improvement of cardiovascular risks: a 6-month randomized, double-blind, and placebo-controlled trial in equol-producing postmenopausal women. Mol Nutr Food Res. 2014;58(4):709-717. doi:10.1002/mnfr.201300499 | Intervention/Exposure; Comparator
1328 | Liu, C, Xue, Y, Wang, Y, et al. Association between dietary patterns and dyslipidemia in adults from the Henan Rural Cohort Study. Asia Pac J Clin Nutr. 2020. 29:299-308. doi:10.6133/apjcn.202007_29(2).0013 | Intervention/Exposure
1329 | Liu, CW. Healthy dietary pattern with daily egg consumption might be the true factor associated with decreased risks of cardiovascular diseases and mortality. Heart. Nov 2018;104(21):1804-1804. doi:10.1136/heartjnl-2018-313774 | Study design
1330 | Liu, L, Nettleton, JA, Bertoni, AG, et al. Dietary pattern, the metabolic syndrome, and left ventricular mass and systolic function: the Multi-Ethnic Study of Atherosclerosis. Am J Clin Nutr. 2009. 90:362-8. doi:10.3945/ajcn.2009.27538 | Study design
1331 | Liu, Q, Wen, Q, Lv, J, et al. The Prospective Associations of Lipid Metabolism-Related Dietary Patterns with the Risk of Diabetes in Chinese Adults. Article. Nutrients. Feb 25 2022;14(5)doi:10.3390/nu14050980 | Intervention/Exposure; Country
1332 | Liu, Q. Impact of different dietary fat sources on blood pressure in Chinese adults. PLoS One. 2021. 16:e0247116. doi:10.1371/journal.pone.0247116 | Country
1333 | Liu, S, Song, Y, Ford, ES, et al. Dietary calcium, vitamin D, and the prevalence of metabolic syndrome in middle-aged and older U.S. women. Diabetes Care. 2005. 28:2926-32. doi:10.2337/diacare.28.12.2926 | Intervention/Exposure; Outcome
1334 | Liu, X, Garban, J, Jones, PJ, et al. Diets Low in Saturated Fat with Different Unsaturated Fatty Acid Profiles Similarly Increase Serum-Mediated Cholesterol Efflux from THP-1 Macrophages in a Population with or at Risk for Metabolic Syndrome: The Canola Oil Multicenter Intervention Trial. Journal of Nutrition. May 2018;148(5):721-728. doi:10.1093/jn/nxy040 | Intervention/Exposure
1335 | Liu, X, Kris-Etherton, PM, West, SG, et al. Effects of canola and high-oleic-acid canola oils on abdominal fat mass in individuals with central obesity. Obesity (Silver Spring). Nov 2016;24(11):2261-2268. doi:10.1002/oby.21584 | Intervention/Exposure; Comparator
1336 | Liu, Y, Poon, S, Seeman, E, et al. Fat from dairy foods and ‘meat’ consumed within recommended levels is associated with favourable serum cholesterol levels in institutionalised older adults. J Nutr Sci. 2019. 8:e10. doi:10.1017/jns.2019.5 | Study design; Health status
1337 | Liu, ZM, Ho, SC, Chen, YM, et al. Effect of soy protein and isoflavones on blood pressure and endothelial cytokines: a 6-month randomized controlled trial among postmenopausal women. Journal of Hypertension. Feb 2013;31(2):384-392. doi:10.1097/HJH.0b013e32835c090 | Intervention/Exposure
1338 | Liu, ZM, Ho, SC, Chen, YM, et al. Effect of whole soy and purified daidzein on ambulatory blood pressure and endothelial function-a 6-month double-blind, randomized controlled trial among Chinese postmenopausal women with prehypertension. Eur J Clin Nutr. 2015. 69:1161-8. doi:10.1038/ejcn.2015.24 | Intervention/Exposure; Comparator
1339 | Liu, ZM, Ho, SC, Chen, YM, et al. The effects of isoflavones combined with soy protein on lipid profiles, C-reactive protein and cardiovascular risk among postmenopausal Chinese women. Nutr Metab Cardiovasc Dis. 2012. 22:712-9. doi:10.1016/j.numecd.2010.11.002 | Intervention/Exposure
1340 | Livingstone KM, Lovegrove JA, Cockcroft JR, Elwood PC, Pickering JE, Givens DI. Does dairy food intake predict arterial stiffness and blood pressure in men?: Evidence from the Caerphilly Prospective Study. Hypertension. 2013;61(1):42-47. doi:10.1161/HYPERTENSIONAHA.111.00026 | Intervention/Exposure; Comparator
1341 | Livingstone, KM, Abbott, G, Bowe, SJ, et al. Diet quality indices, genetic risk and risk of cardiovascular disease and mortality: a longitudinal analysis of 77 004 UK Biobank participants. Article. BMJ Open. Apr 1 2021;11(4):e045362. doi:10.1136/bmjopen-2020-045362 | Intervention/Exposure
1342 | Lizcano F, Valenzuela C. The impact of lean pork meat consumption on cardiovascular risk. Revista Colombiana de Cardiología. 2020;27(4):337-343. doi: 10.1016/j.rccar.2020.01.011 | Publication language
1343 | Lloyd-Williams, F, Mwatsama, M, Ireland, R, et al. Small changes in snacking behaviour: the potential impact on CVD mortality. Public Health Nutr. 2009. 12:871-6. doi:10.1017/s1368980008003054 | Study design; Intervention/Exposure
1344 | Loganathan, R, Vethakkan, SR, Radhakrishnan, AK, et al. Red palm olein supplementation on cytokines, endothelial function and lipid profile in centrally overweight individuals: a randomised controlled trial. Eur J Clin Nutr. 2019. 73:609-616. doi:10.1038/s41430-018-0236-5 | Comparator
1345 | Loo, RL, Zou, X, Appel, LJ, et al. Characterization of metabolic responses to healthy diets and association with blood pressure: application to the Optimal Macronutrient Intake Trial for Heart Health (OmniHeart), a randomized controlled study. Am J Clin Nutr. Mar 1 2018;107(3):323-334. doi:10.1093/ajcn/nqx072 | Intervention/Exposure; Health status
1346 | López EP, Rice C, Weddle DO, Rahill GJ. The relationship among cardiovascular risk factors, diet patterns, alcohol consumption, and ethnicity among women aged 50 years and older. J Am Diet Assoc. 2008;108(2):248-256. doi:10.1016/j.jada.2007.10.043 | Study design
1347 | Lopez-Legarrea, P, De La Iglesia, R, Abete, I, et al. Short-term role of the dietary total antioxidant capacity in two hypocaloric regimes on obese with metabolic syndrome symptoms: the RESMENA randomized controlled trial. Nutr Metab (Lond). Feb 13 2013;10(1):22. doi:10.1186/1743-7075-10-22 | Intervention/Exposure
1348 | López-Miranda, J, Marín, C, Castro, P, et al. The effect of apolipoprotein B xbaI polymorphism on plasma lipid response to dietary fat. Eur J Clin Invest. Aug 2000;30(8):678-84. doi:10.1046/j.1365-2362.2000.00681.x | Intervention/Exposure
1349 | Lorenzen, JK, Astrup, A. Dairy calcium intake modifies responsiveness of fat metabolism and blood lipids to a high-fat diet. Br J Nutr. 2011. 105:1823-31. doi:10.1017/s0007114510005581 | Duration
1350 | Louheranta, AM, Schwab, US, Sarkkinen, ES, et al. Insulin sensitivity after a reduced-fat diet and a monoene-enriched diet in subjects with elevated serum cholesterol and triglyceride concentrations. Nutr Metab Cardiovasc Dis. Aug 2000;10(4):177-87. | Intervention/Exposure; Sample size/Power
1351 | Louheranta, AM, Turpeinen, AK, Schwab, US, et al. A high-stearic acid diet does not impair glucose tolerance and insulin sensitivity in healthy women. Metabolism. 1998. 47:529-34. doi:10.1016/s0026-0495(98)90235-9 | Sample size/Power
1352 | Louheranta, AM, Turpeinen, AK, Vidgren, HM, et al. A high-trans fatty acid diet and insulin sensitivity in young healthy women. Metabolism. 1999. 48:870-5. doi:10.1016/s0026-0495(99)90221-4 | Intervention/Exposure; Sample size/Power
1353 | Louie JC, Flood VM, Rangan AM, et al. Higher regular fat dairy consumption is associated with lower incidence of metabolic syndrome but not type 2 diabetes. Nutr Metab Cardiovasc Dis. 2013;23(9):816-821. doi:10.1016/j.numecd.2012.08.004 | Outcome
1354 | Lovejoy, JC, Bray, GA, Lefevre, M, et al. Consumption of a controlled low-fat diet containing olestra for 9 months improves health risk factors in conjunction with weight loss in obese men: the Ole’ Study. Int J Obes Relat Metab Disord. Oct 2003;27(10):1242-9. doi:10.1038/sj.ijo.0802373 | Intervention/Exposure
1355 | Lovejoy, JC, Most, MM, Lefevre, M, et al. Effect of diets enriched in almonds on insulin action and serum lipids in adults with normal glucose tolerance or type 2 diabetes. Am J Clin Nutr. Nov 2002;76(5):1000-6. doi:10.1093/ajcn/76.5.1000 | Intervention/Exposure
1356 | Lovejoy, JC, Smith, SR, Champagne, CM, et al. Effects of diets enriched in saturated (palmitic), monounsaturated (oleic), or trans (elaidic) fatty acids on insulin sensitivity and substrate oxidation in healthy adults. Diabetes Care. 2002. 25:1283-8. doi:10.2337/diacare.25.8.1283 | Intervention/Exposure; Sample size/Power
1357 | Lu Y, Matsuyama S, Sugawara Y, Sone T, Tsuji I. Dairy intake and incident functional disability among older Japanese adults: the Ohsaki Cohort 2006 Study. Eur J Nutr. 2022;61(5):2627-2637. doi:10.1007/s00394-022-02843-w | Outcome
1358 | Lu Y, Sugawara Y, Tsuji I. Association between dairy intake and risk of incident dementia: the Ohsaki Cohort 2006 Study. Eur J Nutr. 2023;62(7):2751-2761. doi:10.1007/s00394-023-03189-7 | Outcome
1359 | Lu, TM, Chiu, HF, Lu, YY, et al. Efficacy of fermented goat milk on blood pressure in prehypertensive adults: A randomized, placebo-controlled, clinical trial. Journal of Food Biochemistry. Apr 2018;42(2)doi:ARTN e1247410.1111/jfbc.12474 | Intervention/Exposure; Sample size/Power
1360 | Lu, Y, Sugawara, Y, Matsuyama, S, et al. Association of dairy intake with all-cause, cancer, and cardiovascular disease mortality in Japanese adults: a 25-year population-based cohort. Eur J Nutr. 2022. 61:1285-1297. doi:10.1007/s00394-021-02734-6 | Comparator
1361 | Luksiene, DI, Baceviciene, M, Tamosiunas, A. Population-based study in Lithuania: lifestyle factors and risk of metabolic syndrome. Central European Journal of Medicine. Jun 2010;5(3):387-398. doi:10.2478/s11536-010-0007-8 | Study design
1362 | Luo, Y, Wang, J, Sun, L, et al. Isocaloric-restricted Mediterranean Diet and Chinese Diets High or Low in Plants in Adults With Prediabetes. J Clin Endocrinol Metab. Jul 14 2022;107(8):2216-2227. doi:10.1210/clinem/dgac303 | Intervention/Exposure
1363 | Luoto, R, Prättälä, R, Uutela, A, et al. Impact of unhealthy behaviors on cardiovascular mortality in Finland, 1978-1993. Prev Med. 1998. 27:93-100. doi:10.1006/pmed.1997.0249 | Comparator
1364 | Lupton BS, Fønnebø V, Søgaard AJ; Finnmark Intervention Study. The Finnmark Intervention Study: is it possible to change CVD risk factors by community-based intervention in an Arctic village in crisis?. Scand J Public Health. 2003;31(3):178-186. doi:10.1080/14034940210134077 | Intervention/Exposure
1365 | Luque, V, Closa-Monasterolo, R, Grote, V, et al. Dietary patterns acquired in early life are associated with cardiometabolic markers at school age. Clinical Nutrition. 2021. 40:4606-4614. doi:10.1016/j.clnu.2021.06.001 | Intervention/Exposure
1366 | Lüscher, TF. Nutrition, obesity, diabetes, and cardiovascular outcomes: a deadly association. Eur Heart J. Jul 21 2020;41(28):2603-2607. doi:10.1093/eurheartj/ehaa622 | Study design
1367 | Luscombe-Marsh ND, Noakes M, Wittert GA, Keogh JB, Foster P, Clifton PM. Carbohydrate-restricted diets high in either monounsaturated fat or protein are equally effective at promoting fat loss and improving blood lipids. Am J Clin Nutr. 2005;81(4):762-772. doi:10.1093/ajcn/81.4.762 | Intervention/Exposure
1368 | Lutsey, PL, Steffen, LM, Stevens, J. Dietary intake and the development of the metabolic syndrome: the Atherosclerosis Risk in Communities study. Circulation. Feb 12 2008;117(6):754-61. | Outcome
1369 | Lv, C, Wang, Y, Zhou, C, et al. Effects of dietary palm olein on the cardiovascular risk factors in healthy young adults. Food Nutr Res. 2018;62doi:10.29219/fnr.v62.1353 | Sample size/Power
1370 | Lv, J, Yu, C, Guo, Y, et al. Adherence to Healthy Lifestyle and Cardiovascular Diseases in the Chinese Population. J Am Coll Cardiol. Mar 7 2017;69(9):1116-1125. doi:10.1016/j.jacc.2016.11.076 | Intervention/Exposure; Country
1371 | Lv, M, Su, C, Huang, F, et al. Association of Vegetable Consumption with Stroke in China: A Longitudinal Study. Article. Nutrients. Mar 24 2023;15(7)doi:10.3390/nu15071583 3 | Intervention/Exposure; Country
1372 | Lyskjær, L, Overvad, K, Tjønneland, A, et al. Substitutions of Oatmeal and Breakfast Food Alternatives and the Rate of Stroke. Stroke. Jan 2020;51(1):75-81. doi:10.1161/STROKEAHA.119.024977 | Intervention/Exposure
1373 | Lytle, JR, Stanelle, ST, Martin, SE, et al. Assessment of Vascular Function in Response to High-Fat and Low-Fat Ground Beef Consumption in Men. Nutrients. Mar 15 2023;15(6)doi:10.3390/nu15061410 | Sample size/Power
1374 | Lyu, LC, Shieh, MJ, Posner, BM, et al. Relationship between Dietary-Intake, Lipoproteins, and Apolipoproteins in Taipei and Framingham. American Journal of Clinical Nutrition. Nov 1994;60(5):765-774. doi:DOI 10.1093/ajcn/60.5.765 | Intervention/Exposure
1375 | Lyytinen, AT, Yesmean, M, Manninen, S, et al. Fatty fish consumption reduces lipophilic index in erythrocyte membranes and serum phospholipids. Nutr Metab Cardiovasc Dis. Jul 2023;33(7):1453-1460. doi:10.1016/j.numecd.2023.04.011 | Intervention/Exposure
1376 | Ma, Y, Chiriboga, D, Olendzki, BC, et al. Effect of soy protein containing isoflavones on blood lipids in moderately hypercholesterolemic adults: a randomized controlled trial. J Am Coll Nutr. Aug 2005;24(4):275-85. doi:10.1080/07315724.2005.10719475 | Intervention/Exposure; Comparator
1377 | Macdonald, CJ, Madika, AL, Bonnet, F, et al. Cholesterol and Egg Intakes, and Risk of Hypertension in a Large Prospective Cohort of French Women. Nutrients. May 8 2020;12(5)doi:10.3390/nu12051350 | Intervention/Exposure
1378 | MacDonald, CJ, Madika, AL, Bonnet, F, et al. Consumption of cocoa-containing foods and risk of hypertension in French women. Eur J Epidemiol. 2020. 35:465-469. doi:10.1007/s10654-020-00603-w | Comparator
1379 | MacDonald, CJ, Madkia, AL, Mounier-Vehier, C, et al. Associations between saturated fat intake and other dietary macronutrients and incident hypertension in a prospective study of French women. Eur J Nutr. 2023. 62:1207-1215. doi:10.1007/s00394-022-03053-0 | Study design; Outcome
1380 | Machin DR. The hypotensive effects of conventional non-fat dairy products: the role of arterial stiffness [Dissertation]. The University of Texas at Austin. 2014. | Intervention/Exposure
1381 | Machin, DR, Park, W, Alkatan, M, et al. Effects of non-fat dairy products added to the routine diet on vascular function: a randomized controlled crossover trial. Nutr Metab Cardiovasc Dis. Apr 2015;25(4):364-9. doi:10.1016/j.numecd.2015.01.005 | Intervention/Exposure; Comparator
1382 | Machin, DR, Park, W, Alkatan, M, et al. Hypotensive effects of solitary addition of conventional nonfat dairy products to the routine diet: a randomized controlled trial. Am J Clin Nutr. Jul 2014;100(1):80-7. doi:10.3945/ajcn.114.085761 | Intervention/Exposure
1383 | Machlik, ML, Hopstock, LA, Wilsgaard, T, et al. Associations Between Intake of Fermented Dairy Products and Blood Lipid Concentrations Are Affected by Fat Content and Dairy Matrix - The Tromsø Study: Tromsø7. Front Nutr. 2021. 8:773468. doi:10.3389/fnut.2021.773468 | Study design
1384 | Macknin, M, Kong, T, Weier, A, et al. Plant-Based, No-Added-Fat or American Heart Association Diets: Impact on Cardiovascular Risk in Obese Children with Hypercholesterolemia and Their Parents. Journal of Pediatrics. Apr 2015;166(4):953-U264. doi:10.1016/j.jpeds.2014.12.058 | Intervention/Exposure; Sample size/Power
1385 | Macknin, M, Stegmeier, N, Thomas, A, et al. Three Healthy Eating Patterns and Cardiovascular Disease Risk Markers in 9 to 18 Year Olds With Body Mass Index >95%: A Randomized Trial. Clin Pediatr (Phila). Oct 2021;60(11-12):474-484. doi:10.1177/00099228211044841 | Intervention/Exposure
1386 | Madalosso, MM, Martins, NNF, Medeiros, BM, et al. Consumption of ultra-processed foods and cardiometabolic risk factors in Brazilian adolescents: results from ERICA. Eur J Clin Nutr. Nov 2023;77(11):1084-1092. doi:10.1038/s41430-023-01329-0 | Study design; Intervention/Exposure
1387 | Madjd, A, Taylor, MA, Mousavi, N, et al. Comparison of the effect of daily consumption of probiotic compared with low-fat conventional yogurt on weight loss in healthy obese women following an energy-restricted diet: a randomized controlled trial. Am J Clin Nutr. 2016. 103:323-9. doi:10.3945/ajcn.115.120170 | Comparator
1388 | Madsen, MB, Jensen, AM, Schmidt, EB. The effect of a combination of plant sterol-enriched foods in mildly hypercholesterolemic subjects. Clin Nutr. 2007. 26:792-8. doi:10.1016/j.clnu.2007.05.008 | Comparator
1389 | Magkos, F, Rasmussen, SI, Hjorth, MF, et al. Unprocessed red meat in the dietary treatment of obesity: a randomized controlled trial of beef supplementation during weight maintenance after successful weight loss. American Journal of Clinical Nutrition. 2022. 116:1820-1830. doi:10.1093/ajcn/nqac152 | Comparator
1390 | Magriplis, E, Marakis, G, Kotopoulou, S, et al. Trans fatty acid intake increases likelihood of dyslipidemia especially among individuals with higher saturated fat consumption. Reviews in Cardiovascular Medicine. Apr 7 2022;23(4)doi:ARTN 130 | Study design
1391 | Magriplis, E, Sialvera, TE, Papadopoulou, A, et al. Effectiveness and easiness of adherence to behavioural guidelines for diet and lifestyle changes for cholesterol-lowering: the Increasing Adherence of Consumers to Diet & Lifestyle Changes to Lower (LDL) Cholesterol (ACT) randomised controlled trial. J Hum Nutr Diet. Oct 2019;32(5):607-618. doi:10.1111/jhn.12667 | Intervention/Exposure
1392 | Mahdavi A, Trottier J, Barbier O, Lebel M, Rudkowska I. Dairy Intake Modifies the Level of the Bile Acid Precursor and Its Correlation with Serum Proteins Associated with Cholesterol Clearance in Subjects with Hyperinsulinemia. Nutrients. 2023;15(22):4707. Published 2023 Nov 7. doi:10.3390/nu15224707 | Sample size/Power
1393 | Mahon, AK, Flynn, MG, Stewart, LK, et al. Protein intake during energy restriction: effects on body composition and markers of metabolic and cardiovascular health in postmenopausal women. J Am Coll Nutr. Apr 2007;26(2):182-9. doi:10.1080/07315724.2007.10719600 | Sample size/Power
1394 | Maimaitiyiming, M, Yang, H, Li, H, et al. The association of obesity-related dietary patterns and main food groups derived by reduced-rank regression with cardiovascular diseases incidence and all-cause mortality: findings from 116,711 adults. Eur J Nutr. Sep 2023;62(6):2605-2619. doi:10.1007/s00394-023-03177-x | Comparator
1395 | Maiti R, Mohanty RR, Dey A, Maji S, Padhan M, Mishra A. Effect of virgin coconut oil (VCO) on cardiometabolic parameters in patients with dyslipidemia: a randomized, add-on placebo-controlled clinical trial. J Am Nutr Assoc. 2024;43(3);244-251. doi:10.1080/27697061.2023.2256816 | Country
1396 | Maki K, Rains T, Schild A, Dicklin M, Lawless A, Kelley K Park K. Low-fat dairy intake improves endothelial function in subjects with pre-hypertension or stage I hypertension and impaired endothelial dysfunction. The FASEB Journal. 2013. 27(10) | Publication status
1397 | Maki, KC, Butteiger, DN, Rains, TM, et al. Effects of soy protein on lipoprotein lipids and fecal bile acid excretion in men and women with moderate hypercholesterolemia. J Clin Lipidol. Nov-Dec 2010;4(6):531-42. doi:10.1016/j.jacl.2010.09.001 | Intervention/Exposure
1398 | Maki, KC, Palacios, OM, Lindner, E, et al. Replacement of Refined Starches and Added Sugars with Egg Protein and Unsaturated Fats Increases Insulin Sensitivity and Lowers Triglycerides in Overweight or Obese Adults with Elevated Triglycerides. J Nutr. 2017. 147:1267-1274. doi:10.3945/jn.117.248641 | Intervention/Exposure; Duration
1399 | Maki, KC, Shinnick, F, Seeley, MA, et al. Food products containing free tall oil-based phytosterols and oat beta-glucan lower serum total and LDL cholesterol in hypercholesterolemic adults. J Nutr. Mar 2003;133(3):808-13. doi:10.1093/jn/133.3.808 | Intervention/Exposure
1400 | Malpuech-Brugère, C, Mouriot, J, Boue-Vaysse, C, et al. Differential impact of milk fatty acid profiles on cardiovascular risk biomarkers in healthy men and women. Eur J Clin Nutr. 2010. 64:752-9. doi:10.1038/ejcn.2010.73 | Duration
1401 | Mamo, JC, James, AP, Soares, MJ, et al. A low-protein diet exacerbates postprandial chylomicron concentration in moderately dyslipidaemic subjects in comparison to a lean red meat protein-enriched diet. Eur J Clin Nutr. 2005. 59:1142-8. doi:10.1038/sj.ejcn.1602224 | Duration; Sample size/Power
1402 | Mamun, A, Kitzman, H, Dodgen, L. Reducing metabolic syndrome through a community-based lifestyle intervention in African American women. Nutrition Metabolism and Cardiovascular Diseases. Sep 24 2020;30(10):1785-1794. doi:10.1016/j.numecd.2020.06.005 | Intervention/Exposure
1403 | Manatt, MW, Garcia, PA, Kies, C, et al. Studies of women eating diets with different fatty acid composition. II. Urinary eicosanoids and sodium, and blood pressure. J Am Coll Nutr. Aug 1991;10(4):322-6. doi:10.1080/07315724.1991.10718159 | Intervention/Exposure; Sample size/Power
1404 | Manav, M, Su, J, Hughes, K, et al. ω-3 fatty acids arid selenium as coronary heart disease risk modifying factors in Asian Indian and Chinese males. Nutrition. Nov-Dec 2004;20(11-12):967-973. doi:10.1016/j.nut.2004.08.003 | Study design
1405 | Mangravite, LM, Chiu, S, Wojnoonski, K, et al. Changes in atherogenic dyslipidemia induced by carbohydrate restriction in men are dependent on dietary protein source. J Nutr. 2011. 141:2180-5. doi:10.3945/jn.111.139477 | Duration
1406 | Manios, Y, Moschonis, G, Grammatikaki, E, et al. Nutrition education in postmenopausal women: changes in dietary and cardiovascular indices. Maturitas. Nov 20 2006;55(4):338-47. doi:10.1016/j.maturitas.2006.05.006 | Intervention/Exposure
1407 | Mann, JI, Appleby, PN, Key, TJ, et al. Dietary determinants of ischaemic heart disease in health conscious individuals. Heart. Nov 1997;78(5):450-5. doi:10.1136/hrt.78.5.450 | Comparator
1408 | Mannarino, E, Pirro, M, Cortese, C, et al. Effects of a phytosterol-enriched dairy product on lipids, sterols and 8-isoprostane in hypercholesterolemic patients: a multicenter Italian study. Nutr Metab Cardiovasc Dis. 2009. 19:84-90. doi:10.1016/j.numecd.2008.03.012 | Comparator
1409 | Mansouri, E, Asghari, S, Nikooei, P, et al. Effects of virgin coconut oil consumption on serum brain-derived neurotrophic factor levels and oxidative stress biomarkers in adults with metabolic syndrome: a randomized clinical trial. Nutr Neurosci. May 2024;27(5):487-498. doi:10.1080/1028415X.2023.2223390 | Outcome
1410 | Mansouri, M, Pahlavani, N, Sharifi, F, et al. Dairy Consumption in Relation to Hypertension Among a Large Population of University Students: The MEPHASOUS Study. Diabetes Metab Syndr Obes. 2020. 13:1633-1642. doi:10.2147/dmso.S248592 | Study design
1411 | Mantzioris, E, Cleland, LG, Gibson, RA, et al. Biochemical effects of a diet containing foods enriched with n-3 fatty acids. Am J Clin Nutr. Jul 2000;72(1):42-8. doi:10.1093/ajcn/72.1.42 | Study design; Outcome
1412 | Mantzioris, E, James, MJ, Gibson, RA, et al. Dietary substitution with an alpha-linolenic acid-rich vegetable oil increases eicosapentaenoic acid concentrations in tissues. Am J Clin Nutr. 1994. 59:1304-9. doi:10.1093/ajcn/59.6.1304 | Intervention/Exposure
1413 | Marckmann, P, Bladbjerg, EM, Jespersen, J. Dietary fish oil (4 g daily) and cardiovascular risk markers in healthy men. Arterioscler Thromb Vasc Biol. Dec 1997;17(12):3384-91. doi:10.1161/01.atv.17.12.3384 | Intervention/Exposure; Comparator; Sample size/Power
1414 | Margdarinejad, M, Sanagoo, A, Zadeh, FM, et al. Effect of camel milk in comparison with cow milk on blood glucose and lipid profile in patients with type 2 diabetes: A randomized clinical trial. Journal of Nursing and Midwifery Sciences. Jan-Mar 2021;8(1):15-19. doi:10.4103/Jnms.Jnms_29_20 | Study design; Health status
1415 | Margerison, C, Riddell, LJ, McNaughton, SA, et al. Associations between dietary patterns and blood pressure in a sample of Australian adults. Nutr J. 2020. 19:5. doi:10.1186/s12937-019-0519-2 | Intervention/Exposure
1416 | Marin, C, Ramirez, R, Delgado-Lista, J, et al. Mediterranean diet reduces endothelial damage and improves the regenerative capacity of endothelium. American Journal of Clinical Nutrition. 2011. 93:267-274. doi:10.3945/ajcn.110.006866 | Sample size/Power
1417 | Marina, A, Delfino Von Frankenberg, A, Suvag, S, et al. Effects of dietary fat and saturated fat content on liver fat and markers of oxidative stress in overweight/obese men and women under weight-stable conditions. Nutrients. Oct 28 2014;6(11):4678-90. doi:10.3390/nu6114678 | Intervention/Exposure; Sample size/Power
1418 | Markey, O, Vasilopoulou, D, Kliem, KE, et al. Effect of fat-reformulated dairy food consumption on postprandial flow-mediated dilatation and cardiometabolic risk biomarkers compared with conventional dairy: a randomized controlled trial. American journal of clinical nutrition. 2022. 115:679-693. doi:10.1093/ajcn/nqab428 | Intervention/Exposure; Outcome
1419 | Markey, O, Vasilopoulou, D, Kliem, KE, et al. Plasma phospholipid fatty acid profile confirms compliance to a novel saturated fat-reduced, monounsaturated fat-enriched dairy product intervention in adults at moderate cardiovascular risk: a randomized controlled trial. Nutrition journal. 2017. 16:33. doi:10.1186/s12937-017-0249-2 | Intervention/Exposure; Outcome; Comparator
1420 | Markey, O, Vasilopoulou, D, Kliem, KE, et al. Postprandial Fatty Acid Profile, but Not Cardiometabolic Risk Markers, Is Modulated by Dairy Fat Manipulation in Adults with Moderate Cardiovascular Disease Risk: the Randomized Controlled REplacement of SaturatEd fat in dairy on Total cholesterol (RESET) Study. Journal of nutrition. 2021. 151:1755-1768. doi:10.1093/jn/nxab050 | Intervention/Exposure; Duration
1421 | Marklund, M, Leander, K, Vikström, M, et al. Polyunsaturated Fat Intake Estimated by Circulating Biomarkers and Risk of Cardiovascular Disease and All-Cause Mortality in a Population-Based Cohort of 60-Year-Old Men and Women. Circulation. Aug 18 2015;132(7):586-94. doi:10.1161/CIRCULATIONAHA.115.015607 | Intervention/Exposure
1422 | Marklund, M, Magnusdottir, OK, Rosqvist, F, et al. A dietary biomarker approach captures compliance and cardiometabolic effects of a healthy Nordic diet in individuals with metabolic syndrome. J Nutr. Oct 2014;144(10):1642-9. doi:10.3945/jn.114.193771 | Intervention/Exposure
1423 | Marrero, A, Haneuse, S, Golden, CD, et al. Neo-Traditional and Industrialized Dietary Patterns Coexist and Are Differentially Associated with Cardiometabolic Health among Adults in Puerto Rico. Article in Press. J Nutr. Nov 2023;153(11):3259-3269. doi:10.1016/j.tjnut.2023.09.003 | Intervention/Exposure
1424 | Marshall, DA, Vernalis, MN, Remaley, AT, et al. The role of exercise in modulating the impact of an ultralow-fat diet on serum lipids and apolipoproteins in patients with or at risk for coronary artery disease. American Heart Journal. 2006. 151:484-491. doi:10.1016/j.ahj.2005.03.065 | Study design; Intervention/Exposure
1425 | Martin, CL, Siega-Riz, AM, Sotres-Alvarez, D, et al. Maternal Dietary Patterns are Associated with Lower Levels of Cardiometabolic Markers during Pregnancy. Paediatr Perinat Epidemiol. 2016. 30:246-55. doi:10.1111/ppe.12279 | Intervention/Exposure
1426 | Martín-Calvo N, Bes-Rastrollo M, Gómez-Donoso C, et al. Reducción de carnes rojas y procesadas en la población española: ¿cuál es su impacto sobre la mortalidad cardiovascular? [Reduction of red and processed meats in the Spanish population: What is its impact on total and cardiovascular mortality?]. Aten Primaria. 2021;53(2):101950. doi:10.1016/j.aprim.2020.08.006 | Publication language
1427 | Martínez, E, Pardo, JE, Rabadán, A, et al. Effects of Animal Fat Replacement by Emulsified Melon and Pumpkin Seed Oils in Deer Burgers. Foods. Mar 17 2023;12(6)doi:10.3390/foods12061279 | Outcome
1428 | Martínez-González MÁ, Toledo E, Arós F, et al. Extravirgin olive oil consumption reduces risk of atrial fibrillation: the PREDIMED (Prevención con Dieta Mediterránea) trial [published correction appears in Circulation. 2019 Dec 10;140(24):e939. doi: 10.1161/CIR.0000000000000716]. Circulation. 2014;130(1):18-26. doi:10.1161/CIRCULATIONAHA.113.006921 | Intervention/Exposure; Outcome
1429 | Martínez-González MA, Zazpe I, Razquin C, et al. Empirically-derived food patterns and the risk of total mortality and cardiovascular events in the PREDIMED study. Clin Nutr. 2015;34(5):859-867. doi:10.1016/j.clnu.2014.09.006 | Intervention/Exposure
1430 | Martínez-González, MA, Sánchez-Tainta, A, Corella, D, et al. A provegetarian food pattern and reduction in total mortality in the Prevención con Dieta Mediterránea (PREDIMED) study. American journal of clinical nutrition. 2014. 100 Suppl 1:320S-8S. doi:10.3945/ajcn.113.071431 | Intervention/Exposure
1431 | Martínez-González, MA, Sanchez-Villegas, A, De Irala, J, et al. Mediterranean diet and stroke: objectives and design of the SUN project. Seguimiento Universidad de Navarra. Nutr Neurosci. Feb 2002;5(1):65-73. doi:10.1080/10284150290007047 | Study design; Intervention/Exposure
1432 | Martínez-López, S, Sarriá, B, Sierra-Cinos, JL, et al. Realistic intake of a flavanol-rich soluble cocoa product increases HDL-cholesterol without inducing anthropometric changes in healthy and moderately hypercholesterolemic subjects. Food Funct. 2014. 5:364-74. doi:10.1039/c3fo60352k | Intervention/Exposure; Comparator
1433 | Martínez-Ortiz, JA, Fung, TT, Baylin, A, et al. Dietary patterns and risk of nonfatal acute myocardial infarction in Costa Rican adults. Eur J Clin Nutr. 2006. 60:770-7. doi:10.1038/sj.ejcn.1602381 | Intervention/Exposure
1434 | Martini, D, Rosi, A, Tassotti, M, et al. Effect of coffee and cocoa-based confectionery containing coffee on markers of cardiometabolic health: results from the pocket-4-life project. European journal of nutrition. 2021. 60:1453-1463. doi:10.1007/s00394-02002347-5 | Intervention/Exposure; Sample size/Power
1435 | Martini, LA, Wood, RJ. Milk intake and the risk of type 2 diabetes mellitus, hypertension and prostate cancer. Arq Bras Endocrinol Metabol. Jul 2009;53(5):688-94. doi:10.1590/s0004-27302009000500021 | Study design
1436 | Martins, MLB, Kac, G, Silva, RA, et al. Dairy consumption is associated with a lower prevalence of metabolic syndrome among young adults from Ribeirao Preto, Brazil. Nutrition. May 2015;31(5):716-721. doi:10.1016/j.nut.2014.12.017 | Study design
1437 | Maruyama, C, Ezawa, I. The effect of milk and skim milk intake on serum lipids and apoproteins in young females. J Nutr Sci Vitaminol (Tokyo). Feb 1991;37(1):53-62. doi:10.3177/jnsv.37.53 | Duration; Sample size/Power
1438 | Maruyama, C, Nakamura, M, Ito, M, et al. The effect of milk and skim milk intake on serum lipids and apoproteins in postmenopausal females. J Nutr Sci Vitaminol (Tokyo). Apr 1992;38(2):203-13. doi:10.3177/jnsv.38.203 | Duration; Sample size/Power
1439 | Maruyama, C, Nakano, R, Shima, M, et al. Effects of a Japan Diet intake program on metabolic parameters in middle-aged men: a pilot study. Journal of atherosclerosis and thrombosis. 2017. 24:393-401. doi:10.5551/jat.36780 | Study design
1440 | Maruyama, C, Sato, A, Nishikata, Y, et al. Effects of Nutrition Education Program for the Japan Diet on Serum Phospholipid Fatty Acid Compositions in Patients with Dyslipidemia: Re-analysis of Data from a Previous Randomized Controlled Trial. J Atheroscler Thromb. Dec 1 2023;30(12):1849-1869. doi:10.5551/jat.64154 | Intervention/Exposure
1441 | Maruyama, K, Iso, H, Date, C, et al. Dietary patterns and risk of cardiovascular deaths among middle-aged Japanese: JACC Study. Nutrition Metabolism and Cardiovascular Diseases. Jun 2013;23(6):519-527. doi:10.1016/j.numecd.2011.10.007 | Intervention/Exposure
1442 | Marzuki, A, Arshad, F, Razak, TA, et al. Influence of dietary fat on plasma lipid profiles of Malaysian adolescents. Am J Clin Nutr. Apr 1991;53(4 Suppl):1010S-1014S. doi:10.1093/ajcn/53.4.1010S | Study design
1443 | Masala, G, Bendinelli, B, Versari, D, et al. Anthropometric and dietary determinants of blood pressure in over 7000 Mediterranean women: the European Prospective Investigation into Cancer and Nutrition-Florence cohort. Journal of Hypertension. Nov 2008;26(11):2112-2120. doi:10.1097/HJH.0b013e32830ef75c | Study design
1444 | Mashhadi, NS, Saadat, S, Afsharmanesh, MR, et al. Study of association between beverage consumption pattern and lipid profile in shift workers. Diabetes & Metabolic Syndrome-Clinical Research & Reviews. Oct-Dec 2016;10(4):227-229. doi:10.1016/j.dsx.2016.06.011 | Study design
1445 | Mason AE, Saslow LR, Moran PJ, et al. Lipid findings from the Diabetes Education to Lower Insulin, Sugars, and Hunger (DELISH) Study [published correction appears in Nutr Metab (Lond). 2019 Dec 30;16:91. doi: 10.1186/s12986-019-0416-x]. Nutr Metab (Lond). 2019;16:58. Published 2019 Aug 27. doi:10.1186/s12986-019-0383-2 | Intervention/Exposure; Health status
1446 | Mastroiacovo, D, Kwik-Uribe, C, Grassi, D, et al. Cocoa flavanol consumption improves cognitive function, blood pressure control, and metabolic profile in elderly subjects: the Cocoa, Cognition, and Aging (CoCoA) Study-a randomized controlled trial. American journal of clinical nutrition. 2015. 101:538-548. doi:10.3945/ajcn.114.092189 | Intervention/Exposure; Comparator
1447 | Mata, P, Garrido, JA, Ordovas, JM, et al. Effect of dietary monounsaturated fatty acids on plasma lipoproteins and apolipoproteins in women. Am J Clin Nutr. Jul 1992;56(1):77-83. doi:10.1093/ajcn/56.1.77 | Intervention/Exposure; Sample size/Power
1448 | Mata, P, Ordovas, JM, Lopez-Miranda, J, et al. ApoA-IV phenotype affects diet-induced plasma LDL cholesterol lowering. Arterioscler Thromb. Jun 1994;14(6):884-91. doi:10.1161/01.atv.14.6.884 | Intervention/Exposure
1449 | Mata, P, Varela, O, Alonso, R, et al. Monounsaturated and polyunsaturated n-6 fatty acid-enriched diets modify LDL oxidation and decrease human coronary smooth muscle cell DNA synthesis. Arterioscler Thromb Vasc Biol. Oct 1997;17(10):2088-95. doi:10.1161/01.atv.17.10.2088 | Sample size/Power
1450 | Matheson, B, Walker, KZ, Taylor, DM, et al. Effect on serum lipids of monounsaturated oil and margarine in the diet of an Antarctic Expedition. Am J Clin Nutr. Jun 1996;63(6):933-8. doi:10.1093/ajcn/63.6.933 | Study design; Sample size/Power
1451 | Mathur S, Devaraj S, Grundy SM, Jialal I. Cocoa products decrease low density lipoprotein oxidative susceptibility but do not affect biomarkers of inflammation in humans. J Nutr. 2002;132(12):3663-3667. doi:10.1093/jn/132.12.3663 | Study design; Sample size/Power
1452 | Matre . The Association of Meat Intake With All-Cause Mortality and Acute Myocardial Infarction Is Age-Dependent in Patients With Stable Angina Pectoris. Front Nutr. 2021. 8:642612. doi:10.3389/fnut.2021.642612 | Health status
1453 | Matsuo, T, Matsuo, M, Kasai, M, et al. Effects of a liquid diet supplement containing structured medium- and long-chain triacylglycerols on bodyfat accumulation in healthy young subjects. Asia Pac J Clin Nutr. 2001. 10:46-50. doi:10.1046/j.14406047.2001.00196.x | Sample size/Power
1454 | Matsuoka, R, Kamachi, K, Usuda, M, et al. Lactic-fermented egg white improves visceral fat obesity in Japanese subjects-double-blind, placebo-controlled study. Lipids Health Dis. Dec 8 2017;16(1):237. doi:10.1186/s12944-017-0631-2 | Intervention/Exposure; Sample size/Power
1455 | Matsuoka, R, Usuda, M, Masuda, Y, et al. Lactic-fermented egg white reduced serum cholesterol concentrations in mildly hypercholesterolemic Japanese men: a double-blind, parallel-arm design. Lipids Health Dis. May 30 2017;16(1):101. doi:10.1186/s12944-017-0499-1 | Intervention/Exposure
1456 | Matsuyama, S, Sawada, N, Tomata, Y, et al. Association between adherence to the Japanese diet and all-cause and cause-specific mortality: the Japan Public Health Center-based Prospective Study. Eur J Nutr. 2021. 60:1327-1336. doi:10.1007/s00394-020-02330-0 | Intervention/Exposure
1457 | Mattei, J, Noel, SE, Tucker, KL. A meat, processed meat, and French fries dietary pattern is associated with high allostatic load in Puerto Rican older adults. J Am Diet Assoc. 2011. 111:1498-506. doi:10.1016/j.jada.2011.07.006 | Intervention/Exposure
1458 | Mattei, J, Sotos-Prieto, M, Bigornia, SJ, et al. The Mediterranean Diet Score Is More Strongly Associated with Favorable Cardiometabolic Risk Factors over 2 Years Than Other Diet Quality Indexes in Puerto Rican Adults. J Nutr. 2017. 147:661-669. doi:10.3945/jn.116.245431 | Intervention/Exposure
1459 | Matthan, NR, Jalbert, SM, Ausman, LM, et al. Effect of soy protein from differently processed products on cardiovascular disease risk factors and vascular endothelial function in hypercholesterolemic subjects. Am J Clin Nutr. 2007. 85:960-6. doi:10.1093/ajcn/85.4.960 | Sample size/Power
1460 | Matthews, LA, Rovio, SP, Jaakkola, JM, et al. Longitudinal effect of 20-year infancy-onset dietary intervention on food consumption and nutrient intake: the randomized controlled STRIP study. European journal of clinical nutrition. 2019. 73:937-949. doi:10.1038/s41430-018-0350-4 | Outcome; Population
1461 | Matveyenko A, Seid H, Kim K, et al. Association of free-living diet composition with plasma lipoprotein(a) levels in healthy adults. Lipids in health and disease. 2023;22(1):144. doi: 10.1186/s12944-023-01884-2 | Study design; Intervention/Exposure
1462 | Matvienko, OA, Lewis, DS, Swanson, M, et al. A single daily dose of soybean phytosterols in ground beef decreases serum total cholesterol and LDL cholesterol in young, mildly hypercholesterolemic men. Am J Clin Nutr. Jul 2002;76(1):57-64. doi:10.1093/ajcn/76.1.57 | Intervention/Exposure; Comparator
1463 | Mauger, JF, Lichtenstein, AH, Ausman, LM, et al. Effect of different forms of dietary hydrogenated fats on LDL particle size. Am J Clin Nutr. Sep 2003;78(3):370-5. doi:10.1093/ajcn/78.3.370 | Duplicate
1464 | Mayneris-Perxachs, J, Sala-Vila, A, Chisaguano, M, et al. Effects of 1-year intervention with a Mediterranean diet on plasma fatty acid composition and metabolic syndrome in a population at high cardiovascular risk. PloS one. 2014. 9:e85202. doi:10.1371/journal.pone.0085202 | Intervention/Exposure; Comparator
1465 | Mayoral, P, Martinez-Salgado, CS, Santiago, JM, et al. Effect of ham protein substitution on oxidative stress in older adults. J Nutr Health Aging. 2003;7(2):84-9. | Sample size/Power
1466 | Mazidi, M, Mikhailidis, DP, Sattar, N, et al. Association of types of dietary fats and all-cause and cause-specific mortality: A prospective cohort study and meta-analysis of prospective studies with 1,164,029 participants. Clin Nutr. Dec 2020;39(12):3677-3686. doi:10.1016/j.clnu.2020.03.028 | Study design; Intervention/Exposure
1467 | McAfee, AJ, McSorley, EM, Cuskelly, GJ, et al. Red meat from animals offered a grass diet increases plasma and platelet n-3 PUFA in healthy consumers. Br J Nutr. 2011. 105:80-9. doi:10.1017/s0007114510003090 | Outcome; Sample size/Power
1468 | McAuley, KA, Hopkins, CM, Smith, KJ, et al. Comparison of high-fat and high-protein diets with a high-carbohydrate diet in insulin-resistant obese women. Diabetologia. Jan 2005;48(1):8-16. doi:10.1007/s00125-004-1603-4 | Intervention/Exposure
1469 | McCarron, DA. Diet and blood pressure-the paradigm shift. Science. Aug 14 1998;281(5379):933-4. doi:10.1126/science.281.5379.933 | Study design
1470 | McColley, SP, Georgopoulos, A, Young, LR, et al. A high-fat diet and the threonine-encoding allele (Thr54) polymorphism of fatty acid-binding protein 2 reduce plasma triglyceride-rich lipoproteins. Nutr Res. Jul 2011;31(7):503-8. doi:10.1016/j.nutres.2011.06.003 | Intervention/Exposure; Sample size/Power
1471 | McCreadie RG. Diet and cardiovascular risk: descriptive study and randomized controlled trial. Psychiatric News. 2004;39(4): doi:10.1176/pn.39.4.0074 | Publication status
1472 | McCullough, ML, Feskanich, D, Rimm, EB, et al. Adherence to the Dietary Guidelines for Americans and risk of major chronic disease in men. Am J Clin Nutr. Nov 2000;72(5):1223-31. doi:10.1093/ajcn/72.5.1223 | Intervention/Exposure; Outcome
1473 | McCullough, ML, Gapstur, SM, Shah, R, et al. Association between red and processed meat intake and mortality among colorectal cancer survivors. J Clin Oncol. 2013. 31:2773-82. doi:10.1200/jco.2013.49.1126 | Health status
1474 | McDaniel, J, Askew, W, Bennett, D, et al. Bison meat has a lower atherogenic risk than beef in healthy men. Nutr Res. 2013. 33:293-302. doi:10.1016/j.nutres.2013.01.007 | Sample size/Power
1475 | McGavin, JK, Mann, JI, Skeaff, CM, et al. Comparison of a vitamin E-rich diet and supplemental vitamin E on measures of vitamin E status and lipoprotein profile. Eur J Clin Nutr. 2001. 55:555-61. doi:10.1038/sj.ejcn.1601182 | Intervention/Exposure
1476 | McKiernan, F, Lokko, P, Kuevi, A, et al. Effects of peanut processing on body weight and fasting plasma lipids. Br J Nutr. Aug 2010;104(3):418-26. doi:10.1017/S0007114510000590 | Study design; Intervention/Exposure
1477 | McLaughlin, T, Carter, S, Lamendola, C, et al. Effects of moderate variations in macronutrient composition on weight loss and reduction in cardiovascular disease risk in obese, insulin-resistant adults. Am J Clin Nutr. Oct 2006;84(4):813-21. doi:10.1093/ajcn/84.4.813 | Intervention/Exposure
1478 | McNamara, DJ. Palm oil and health: a case of manipulated perception and misuse of science. J Am Coll Nutr. 2010. 29:240s-244s. doi:10.1080/07315724.2010.10719840 | Study design
1479 | McNaughton, SA, Ball, K, Crawford, D, et al. An index of diet and eating patterns is a valid measure of diet quality in an Australian population. Journal of Nutrition. Jan 2008;138(1):86-93. doi:DOI 10.1093/jn/138.1.86 | Study design; Outcome
1480 | McNaughton, SA, Mishra, GD, Brunner, EJ. Food patterns associated with blood lipids are predictive of coronary heart disease: the Whitehall II study. Br J Nutr. 2009. 102:619-24. doi:10.1017/s0007114509243030 | Study design; Intervention/Exposure
1481 | McNaughton, SA, Mishra, GD, Stephen, AM, et al. Dietary patterns throughout adult life are associated with body mass index, waist circumference, blood pressure, and red cell folate. J Nutr. 2007. 137:99-105. doi:10.1093/jn/137.1.99 | Intervention/Exposure
1482 | Meckling, KA, Gauthier, M, Grubb, R, et al. Effects of a hypocaloric, low-carbohydrate diet on weight loss, blood lipids, blood pressure, glucose tolerance, and body composition in free-living overweight women. Can J Physiol Pharmacol. Nov 2002;80(11):1095-105. doi:10.1139/y02-140 | Study design; Sample size/Power
1483 | Meckling, KA, O’Sullivan, C, Saari, D. Comparison of a low-fat diet to a low-carbohydrate diet on weight loss, body composition, and risk factors for diabetes and cardiovascular disease in free-living, overweight men and women. J Clin Endocrinol Metab. 2004. 89:2717-23. doi:10.1210/jc.2003-031606 | Intervention/Exposure
1484 | Medenwald, D, Kluttig, A, Lacruz, ME, et al. Serum dietary fatty acids and coronary heart disease risk – A nested case-control-study within the CARLA cohort. Nutrition, Metabolism and Cardiovascular Diseases. 2019. 29:152-158. doi:10.1016/j.numecd.2018.10.006 | Intervention/Exposure
1485 | Meier, T, Gräfe, K, Senn, F, et al. Cardiovascular mortality attributable to dietary risk factors in 51 countries in the WHO European Region from 1990 to 2016: a systematic analysis of the Global Burden of Disease Study. European Journal of Epidemiology. 2019. 34:37-55. doi:10.1007/s10654-018-0473-x | Study design; Intervention/Exposure
1486 | Mekki, N, Dubois, C, Charbonnier, M, et al. Effects of lowering fat and increasing dietary fiber on fasting and postprandial plasma lipids in hypercholesterolemic subjects consuming a mixed Mediterranean-Western diet. Am J Clin Nutr. 1997. 66:1443-51. doi:10.1093/ajcn/66.6.1443 | Intervention/Exposure; Sample size/Power
1487 | Meksawan, K, Pendergast, DR, Leddy, JJ, et al. Effect of low and high fat diets on nutrient intakes and selected cardiovascular risk factors in sedentary men and women. J Am Coll Nutr. Apr 2004;23(2):131-40. doi:10.1080/07315724.2004.10719353 | Sample size/Power
1488 | Melanson, K, Gootman, J, Myrdal, A, et al. Weight loss and total lipid profile changes in overweight women consuming beef or chicken as the primary protein source. Nutrition. 2003. 19:409-14. doi:10.1016/s0899-9007(02)01080-8 | Sample size/Power
1489 | Mena-Sánchez, G, Babio, N, Martínez-González, MÁ, et al. Fermented dairy products, diet quality, and cardio-metabolic profile of a Mediterranean cohort at high cardiovascular risk. Nutr Metab Cardiovasc Dis. 2018. 28:1002-1011. doi:10.1016/j.numecd.2018.05.006 | Study design
1490 | Mendelian Randomization of Dairy Consumption Working, Group, Charge consortium. Dairy Intake and Body Composition and Cardiometabolic Traits among Adults: Mendelian Randomization Analysis of 182041 Individuals from 18 Studies. Clin Chem. 2019. 65:751-760. doi:10.1373/clinchem.2018.300335 | Study design; Comparator
1491 | Mendis, S, Kumarasunderam, R. The effect of daily consumption of coconut fat and soya-bean fat on plasma lipids and lipoproteins of young normolipidaemic men. Br J Nutr. 1990. 63:547-52. doi:10.1079/bjn19900141 | Sample size/Power
1492 | Mendis, S, Samarajeewa, U, Thattil, RO. Coconut fat and serum lipoproteins: effects of partial replacement with unsaturated fats. Br J Nutr. 2001. 85:583-9. doi:10.1079/bjn2001331 | Country
1493 | Mendonça RD, Lopes AC, Pimenta AM, Gea A, Martinez-Gonzalez MA, Bes-Rastrollo M. Ultra-Processed Food Consumption and the Incidence of Hypertension in a Mediterranean Cohort: The Seguimiento Universidad de Navarra Project. Am J Hypertens. 2017;30(4):358-366. doi:10.1093/ajh/hpw137 | Intervention/Exposure
1494 | Meneton, P, Kesse-Guyot, E, Fezeu, L, et al. Distinctive unhealthy eating pattern in free-living middle-aged hypertensives when compared with dyslipidemic or overweight patients. Journal of Hypertension. Aug 2013;31(8):1554-1563. doi:10.1097/HJH.0b013e32836130f8 | Study design
1495 | Meng, T, Kubow, S, Nielsen, DE. Common variants in the CD36 gene are associated with dietary fat intake, high-fat food consumption and serum triglycerides in a cohort of Quebec adults. Int J Obes (Lond). Jun 2021;45(6):1193-1202. doi:10.1038/s41366-021-00766-w | Intervention/Exposure; Outcome
1496 | Mennen, LI, Lafay, L, Feskens, EJM, et al. Possible protective effect of bread and dairy products on the risk of the metabolic syndrome. Nutrition Research. Mar 2000;20(3):335-347. doi:Doi 10.1016/S0271-5317(00)00127-5 | Study design
1497 | Menotti, A, Alberti-Fidanza, A, Fidanza, F, et al. Factor analysis in the identification of dietary patterns and their predictive role in morbid and fatal events. Public Health Nutr. 2012. 15:1232-9. doi:10.1017/s1368980011003235 | Intervention/Exposure; Outcome
1498 | Mensink, RP, de Jong, A, Lütjohann, D, et al. Plant stanols dose-dependently decrease LDL-cholesterol concentrations, but not cholesterol-standardized fat-soluble antioxidant concentrations, at intakes up to 9 g/d. Am J Clin Nutr. 2010. 92:24-33. doi:10.3945/ajcn.2009.29143 | Intervention/Exposure; Comparator
1499 | Mensink, RP, Ebbing, S, Lindhout, M, et al. Effects of plant stanol esters supplied in low-fat yoghurt on serum lipids and lipoproteins, non-cholesterol sterols and fat soluble antioxidant concentrations. Atherosclerosis. 2002. 160:205-13. doi:10.1016/s0021-9150(01)00562-7 | Intervention/Exposure; Duration
1500 | Mente, A, Dehghan, M, Rangarajan, S, et al. Diet, cardiovascular disease, and mortality in 80 countries. Eur Heart J. Jul 21 2023;44(28):2560-2579. doi:10.1093/eurheartj/ehad269 | Intervention/Exposure
1501 | Meral Koc, B, Yilmaz Akyuz, E, Ozlu, T. The effect of coconut oil on anthropometric measurements and irisin levels in overweight individuals. Int J Obes (Lond). 2022. 46:1735-1741. doi:10.1038/s41366-022-01177-1 | Comparator
1502 | Merrill, RM, Aldana, SG. Consequences of a plant-based diet with low dairy consumption on intake of bone-relevant nutrients. J Womens Health (Larchmt). 2009. 18:691-8. doi:10.1089/jwh.2008.1020 | Intervention/Exposure; Outcome
1503 | Mertens, E, Markey, O, Geleijnse, JM, et al. Dietary Patterns in Relation to Cardiovascular Disease Incidence and Risk Markers in a Middle-Aged British Male Population: Data from the Caerphilly Prospective Study. Nutrients. Jan 18 2017;9(1)doi:10.3390/nu9010075 | Intervention/Exposure
1504 | Metz, JA, Kris-Etherton, PM, Morris, CD, et al. Dietary compliance and cardiovascular risk reduction with a prepared meal plan compared with a self-selected diet. Am J Clin Nutr. Aug 1997;66(2):373-85. doi:10.1093/ajcn/66.2.373 | Intervention/Exposure
1505 | Metzgar, CJ, Nickols-Richardson, SM. Effects of nutrition education on weight gain prevention: a randomized controlled trial. Nutr J. 2016. 15:31. doi:10.1186/s12937-016-0150-4 | Intervention/Exposure
1506 | Meydani, SN, Lichtenstein, AH, Cornwall, S, et al. Immunologic effects of national cholesterol education panel step-2 diets with and without fish-derived N-3 fatty acid enrichment. J Clin Invest. 1993. 92:105-13. doi:10.1172/jci116537 | Intervention/Exposure; Comparator
1507 | Meyer, BJ, Lane, AE, Mann, NJ. Comparison of seal oil to tuna oil on plasma lipid levels and blood pressure in hypertriglyceridaemic subjects. Lipids. Sep 2009;44(9):827-35. doi:10.1007/s11745-009-3333-3 | Intervention/Exposure
1508 | Meyer, J, Döring, A, Herder, C, et al. Dietary patterns, subclinical inflammation, incident coronary heart disease and mortality in middle-aged men from the MONICA/KORA Augsburg cohort study. Eur J Clin Nutr. 2011. 65:800-7. doi:10.1038/ejcn.2011.37 | Intervention/Exposure
1509 | Mhurchú, CN, Margetts, BM, Speller, V. Randomized clinical trial comparing the effectiveness of two dietary interventions for patients with hyperlipidaemia. Clin Sci (Lond). Oct 1998;95(4):479-87. | Intervention/Exposure
1510 | Mi, B, Wen, X, Li, S, et al. Vegetable dietary pattern associated with low risk of preeclampsia possibly through reducing proteinuria. Pregnancy Hypertens. 2019. 16:131-138. doi:10.1016/j.preghy.2019.04.001 | Intervention/Exposure; Outcome
1511 | Micha, R, Peñalvo, JL, Cudhea, F, et al. Association Between Dietary Factors and Mortality From Heart Disease, Stroke, and Type 2 Diabetes in the United States. Jama. 2017. 317:912-924. doi:10.1001/jama.2017.0947 | Intervention/Exposure; Comparator
1512 | Michaëlsson, K, Baron, JA, Byberg, L, et al. Combined associations of body mass index and adherence to a Mediterranean-like diet with all-cause and cardiovascular mortality: A cohort study. PLoS Med. Sep 2020;17(9):e1003331. doi:10.1371/journal.pmed.1003331 | Intervention/Exposure
1513 | Michels, KB, Wolk, A. A prospective study of variety of healthy foods and mortality in women. Int J Epidemiol. Aug 2002;31(4):847-54. doi:10.1093/ije/31.4.847 | Intervention/Exposure
1514 | Michielsen, Ccjr, Hangelbroek, RWJ, Feskens, EJM, et al. Disentangling the Effects of Monounsaturated Fatty Acids from Other Components of a Mediterranean Diet on Serum Metabolite Profiles: A Randomized Fully Controlled Dietary Intervention in Healthy Subjects at Risk of the Metabolic Syndrome. Mol Nutr Food Res. 2019. 63:e1801095. doi:10.1002/mnfr.201801095 | Intervention/Exposure; Sample size/Power
1515 | Midgette AS, Baron JA, Rohan TE. Do cigarette smokers have diets that increase their risks of coronary heart disease and cancer?. Am J Epidemiol. 1993;137(5):521-529. doi:10.1093/oxfordjournals.aje.a116705 | Intervention/Exposure
1516 | Mielgo-Ayuso, J, Collado, PS, Urdampilleta, A, et al. Changes induced by diet and nutritional intake in the lipid profile of female professional volleyball players after 11 weeks of training. J Int Soc Sports Nutr. 2013. 10:55. doi:10.1186/1550-2783-10-55 | Intervention/Exposure; Duration
1517 | Miettinen, TA, Puska, P, Gylling, H, et al. Reduction of serum cholesterol with sitostanol-ester margarine in a mildly hypercholesterolemic population. N Engl J Med. Nov 16 1995;333(20):1308-12. doi:10.1056/NEJM199511163332002 | Intervention/Exposure; Comparator
1518 | Migliaretti, G, Ame, C, Ciullo, S, et al. Metabolic and psychological effects of short-term increased consumption of less-processed foods in daily diets: A Pilot Study. Diabetes Metab. Feb 2020;46(1):66-69. doi:10.1016/j.diabet.2019.07.002 | Intervention/Exposure
1519 | Mihrshahi, S, Ding, D, Gale, J, et al. Vegetarian diet and all-cause mortality: Evidence from a large population-based Australian cohort - the 45 and Up Study. Prev Med. 2017. 97:1-7. doi:10.1016/j.ypmed.2016.12.044 | Intervention/Exposure
1520 | Mikelsaar, M, Hutt, P, Shchepetova, J, et al. [Effect of probiotic Heart cheese “Harmony" comprising bacteria L. plantarum TENSIA DSM 21380 on blood pressure and metabolic health indices]. Vopr Pitan. 2012;81(3):74-81. | Study design; Duration; Comparator
1521 | Mikkilä, V, Räsänen, L, Laaksonen, MM, et al. Long-term dietary patterns and carotid artery intima media thickness: the Cardiovascular Risk in Young Finns Study. Br J Nutr. 2009. 102:1507-12. doi:10.1017/s000711450999064x | Intervention/Exposure
1522 | Mikkilä, V, Räsänen, L, Raitakari, OT, et al. Consistent dietary patterns identified from childhood to adulthood: the cardiovascular risk in Young Finns Study. Br J Nutr. 2005. 93:923-31. doi:10.1079/bjn20051418 | Intervention/Exposure; Outcome
1523 | Mikkilä, V, Räsänen, L, Raitakari, OT, et al. Longitudinal changes in diet from childhood into adulthood with respect to risk of cardiovascular diseases: The Cardiovascular Risk in Young Finns Study. European Journal of Clinical Nutrition. Jul 2004;58(7):1038-1045. doi:10.1038/sj.ejcn.1601929 | Intervention/Exposure
1524 | Mikkilä, V, Räsänen, L, Raitakari, OT, et al. Major dietary patterns and cardiovascular risk factors from childhood to adulthood. The Cardiovascular Risk in Young Finns Study. Br J Nutr. 2007. 98:218-25. doi:10.1017/s0007114507691831 | Intervention/Exposure
1525 | Milanlouei, S, Menichetti, G, Li, Y, et al. A systematic comprehensive longitudinal evaluation of dietary factors associated with acute myocardial infarction and fatal coronary heart disease. Nat Commun. Nov 27 2020;11(1):6074. doi:10.1038/s41467-020-19888-2 | Intervention/Exposure; No confounder adjustment
1526 | Millen, BE, Pencina, MJ, Kimokoti, RW, et al. Nutritional risk and the metabolic syndrome in women: opportunities for preventive intervention from the Framingham Nutrition Study. Am J Clin Nutr. Aug 2006;84(2):434-41. doi:10.1093/ajcn/84.1.434 | Intervention/Exposure
1527 | Millen, BE, Quatromoni, PA, Nam, BH, et al. Dietary patterns, smoking, and subclinical heart disease in women: opportunities for primary prevention from the Framingham Nutrition Studies. J Am Diet Assoc. Feb 2004;104(2):208-14. doi:10.1016/j.jada.2003.11.007 | Intervention/Exposure
1528 | Miller Iii, ER, Appel, LJ, Risby, TH. Effect of dietary patterns on measures of lipid peroxidation: Results from a randomized clinical trial. Circulation. 1998. 98:2390-2395. doi:10.1161/01.CIR.98.22.2390 | Intervention/Exposure
1529 | Miller, ER, 3rd, Erlinger, TP, Sacks, et al. A dietary pattern that lowers oxidative stress increases antibodies to oxidized LDL: results from a randomized controlled feeding study. Atherosclerosis. 2005. 183:175-82. doi:10.1016/j.atherosclerosis.2005.04.001 | Intervention/Exposure
1530 | Miller, ER, Cooper, LA, Carson, KA, et al. A Dietary Intervention in Urban African Americans: Results of the “five Plus Nuts and Beans" Randomized Trial. American Journal of Preventive Medicine. 2016. 50:87-95. doi:10.1016/j.amepre.2015.06.010 | Intervention/Exposure
1531 | Miller, JC, Smith, C, Williams, SM, et al. Trends in serum total cholesterol and dietary fat intakes in New Zealand between 1989 and 2009. Australian and New Zealand Journal of Public Health. Jun 2016;40(3):263-269. doi:10.1111/1753-6405.12504 | Study design
1532 | Miller, M, Beach, V, Sorkin, JD, et al. Comparative effects of three popular diets on lipids, endothelial function, and C-reactive protein during weight maintenance. J Am Diet Assoc. Apr 2009;109(4):713-7. doi:10.1016/j.jada.2008.12.023 | Intervention/Exposure; Sample size/Power
1533 | Miller, M, Teter, B, Dolinar, C, et al. An NCEP II diet reduces postprandial triacylglycerol in normocholesterolemic adults. J Nutr. 1998. 128:582-6. doi:10.1093/jn/128.3.582 | Intervention/Exposure; Sample size/Power
1534 | Miller, SL, Reber, RJ, Chapman-Novakofski, K. Prevalence of CVD risk factors and impact of a two-year education program for premenopausal women. Womens Health Issues. Nov-Dec 2001;11(6):486-93. doi:10.1016/s1049-3867(01)00127-x | Intervention/Exposure
1535 | Min, Y, Blois, A, Geppert, J, et al. Dietary fat intake, circulating and membrane fatty acid composition of healthy Norwegian men and women. J Hum Nutr Diet. Feb 2014;27(1):69-75. doi:10.1111/jhn.12105 | Study design; Intervention/Exposure
1536 | Mirmiran P, Estaki S, Yadegari A, Golzarand M, Azizi F. Adherence to a modified nordic diet and the risk of cardiovascular events in a non-nordic population: a prospective cohort study. Eur J Clin Nutr. Sep 2023;77(9):919-924. doi:10.1038/s41430-023-01325-4 | Comparator
1537 | Mirmiran, P, Gaeini, Z, Feizy, Z, et al. Dietary fatty acid patterns and risk of metabolic syndrome: Tehran lipid and glucose study. Eur J Med Res. Sep 20 2023;28(1):358. doi:10.1186/s40001-023-01348-4 | Intervention/Exposure
1538 | Mirmiran, P, Aghayan, M, Bakhshi, B, et al. Socioeconomic status and lifestyle factors modifies the association between snack foods intake and incidence of metabolic syndrome. Nutrition Journal. Jul 22 2021;20(1)doi:ARTN 7010.1186/s12937-021-00728-y | Intervention/Exposure
1539 | Mirmiran, P, Asghari, G, Farhadnejad, H, et al. Low carbohydrate diet is associated with reduced risk of metabolic syndrome in Tehranian adults. International Journal of Food Sciences and Nutrition. May 2017;68(3):358-365. doi:10.1080/09637486.2016.1242119 | Intervention/Exposure
1540 | Mirmiran, P, Azadbakht, L, Azizi, F. Dietary quality-adherence to the dietary guidelines in Tehranian adolescents: Tehran Lipid and Glucose Study. Int J Vitam Nutr Res. May 2005;75(3):195-200. doi:10.1024/0300-9831.75.3.195 | Intervention/Exposure; Country
1541 | Mirmiran, P, Bahadoran, Z, Delshad, H, et al. Effects of energy-dense nutrient-poor snacks on the incidence of metabolic syndrome: a prospective approach in Tehran Lipid and Glucose Study. Nutrition. May 2014;30(5):538-43. doi:10.1016/j.nut.2013.09.014 | Intervention/Exposure; Outcome
1542 | Mirmiran, P, Bahadoran, Z, Mirzaei, S, et al. Dietary Intake, Changes in Lipid Parameters and the Risk of Hypertriglyceridemia: A Prospective Approach in the Tehran Lipid and Glucose Study. Int J Vitam Nutr Res. 2014;84(5-6):269-76. doi:10.1024/0300-9831/a000213 | Intervention/Exposure
1543 | Mirmiran, P, Bahadoran, Z, Vakili, AZ, et al. Western dietary pattern increases risk of cardiovascular disease in Iranian adults: a prospective population-based study. Appl Physiol Nutr Metab. 2017. 42:326-332. doi:10.1139/apnm-2016-0508 | Intervention/Exposure
1544 | Mirmiran, P, Bakhshi, B, Hosseinpour-Niazi, S, et al. Does the association between patterns of fruit and vegetables and metabolic syndrome incidence vary according to lifestyle factors and socioeconomic status?. Nutrition, Metabolism and Cardiovascular Diseases. 2020. 30:1322-1336. doi:10.1016/j.numecd.2020.04.008 | Intervention/Exposure
1545 | Mirmiran, P, Farhadnejad, H, Teymoori, F, et al. The association of dietary diabetes risk reduction score and its components with risk of metabolic syndrome incident in Tehranian adults. BMC Endocr Disord. Oct 20 2021;21(1):206. doi:10.1186/s12902-021-00872-w | Intervention/Exposure; Outcome
1546 | Mirmiran, P, Hajifaraji, M, Bahadoran, Z, et al. Dietary protein intake is associated with favorable cardiometabolic risk factors in adults: Tehran Lipid and Glucose Study. Nutrition Research. Mar 2012;32(3):169-176. doi:10.1016/j.nutres.2012.01.003 | Intervention/Exposure
1547 | Mirmiran, P, Houshialsadat, Z, Bahadoran, Z, et al. Association of dietary fatty acids and the incidence risk of cardiovascular disease in adults: the Tehran Lipid and Glucose Prospective Study. BMC Public Health. 2020. 20:1743. doi:10.1186/s12889-020-09824-w | Intervention/Exposure
1548 | Mirmiran, P, Moslehi, N, Mahmoudof, H, et al. A Longitudinal Study of Adherence to the Mediterranean Dietary Pattern and Metabolic Syndrome in a Non-Mediterranean Population. Article. Int J Endocrinol Metab. Jul 2015;13(3):e26128. doi:10.5812/ijem.26128v | Intervention/Exposure
1549 | Mirmiran, P, Ramezankhani, A, Azizi, F. Combined effects of saturated fat and cholesterol intakes on serum lipids: Tehran Lipid and Glucose Study. Nutrition. May 2009;25(5):526-31. doi:10.1016/j.nut.2008.11.01 | Study design; Intervention/Exposure
1550 | Mirmiran, P, Yuzbashian, E, Aghayan, M, et al. A Prospective Study of Dietary Meat Intake and Risk of Incident Chronic Kidney Disease. J Ren Nutr. Mar 2020;30(2):111-118. doi:10.1053/j.jrn.2019.06.008 | Outcome
1551 | Mirmiran, P, Ziadlou, M, Karimi, S, et al. The association of dietary patterns and adherence to WHO healthy diet with metabolic syndrome in children and adolescents: Tehran lipid and glucose study. BMC Public Health. 2019. 19:1457. doi:10.1186/s12889-019-7779-9 | Intervention/Exposure; Outcome
1552 | Mishra, S, Xu, J, Agarwal, U, et al. A multicenter randomized controlled trial of a plant-based nutrition program to reduce body weight and cardiovascular risk in the corporate setting: the GEICO study. Eur J Clin Nutr. Jul 2013;67(7):718-24. doi:10.1038/ejcn.2013.92 | Intervention/Exposure
1553 | Misirli, G, Benetou, V, Lagiou, P, et al. Relation of the traditional mediterranean diet to cerebrovascular disease in a mediterranean population. American Journal of Epidemiology. 2012. 176:1185-1192. doi:10.1093/aje/kws205 | Comparator
1554 | Mita, T, Someya, Y, Osonoi, Y, et al. Lower intake of saturated fatty acids is associated with persistently higher arterial stiffness in patients with type 2 diabetes. J Diabetes Investig. 2021. 12:226-233. doi:10.1111/jdi.13347 | Health status
1555 | Mitchell, JH, Collins, AR. Effects of a soy milk supplement on plasma cholesterol levels and oxidative DNA damage in men-a pilot study. Eur J Nutr. 1999. 38:143-8. doi:10.1007/s003940050055 | Sample size/Power
1556 | Mitrou, PN, Kipnis, V, Thiébaut, AC, et al. Mediterranean dietary pattern and prediction of all-cause mortality in a US population: results from the NIH-AARP Diet and Health Study. Arch Intern Med. 2007. 167:2461-8. doi:10.1001/archinte.167.22.2461 | Intervention/Exposure
1557 | Miura, K, Greenland, P, Stamler, J, et al. Relation of vegetable, fruit, and meat intake to 7-year blood pressure change in middle-aged men: the Chicago Western Electric Study. Am J Epidemiol. 2004. 159:572-80. doi:10.1093/aje/kwh085 | Intervention/Exposure; Comparator
1558 | Miyagawa, N, Tsubota-Utsugi, M, Tsuboyama-Kasaoka, N, et al. Seven-year incidence of new-onset hypertension by frequency of dairy intake among survivors of the Great East Japan Earthquake. Hypertension Research. Sep 2022;45(9):1459-1467. doi:10.1038/s41440-022-00933-0 | Intervention/Exposure; Comparator
1559 | Mizushima, S, Ohshige, K, Watanabe, J, et al. Randomized controlled trial of sour milk on blood pressure in borderline hypertensive men. Am J Hypertens. 2004. 17:701-6. doi:10.1016/j.amjhyper.2004.03.674 | Comparator
1560 | Mochari-Greenberger, H, Terry, MB, Mosca, L. Sex, age, and race/ethnicity do not modify the effectiveness of a diet intervention among family members of hospitalized cardiovascular disease patients. J Nutr Educ Behav. 2011. 43:366-73. doi:10.1016/j.jneb.2011.01.014 | Intervention/Exposure
1561 | Mogollon, JA, Bujold, E, Lemieux, S, et al. Blood pressure and endothelial function in healthy, pregnant women after acute and daily consumption of flavanol-rich chocolate: a pilot, randomized controlled trial. Nutr J. 2013. 12:41. doi:10.1186/1475-2891-12-41 | Intervention/Exposure; Comparator
1562 | Mohamedou, MMO, Tacha, A, Messal, ME, et al. The consumption of argan oil induces a lipid-lowering effect in dyslipidemic patients. Mediterranean journal of nutrition and metabolism. 2012. 5:143-147. doi:10.1007/s12349-011-0080-9 | Duration
1563 | Mohammad Moradi S, Javidan A, Naji Isfahani H. Effects of probiotic ultra-filtered feta cheese and raw chicory root extract on lipid profile in healthy adult volunteers: a triple-blinded randomized controlled trial. Mediterranean J Nutr Metab. 2013;6:199-206. | Comparator
1564 | Mohammadi Hosseinabadi S, Nasrollahzadeh J. Effects of diets rich in ghee or olive oil on cardiometabolic risk factors in healthy adults: a two-period, crossover, randomised trial. Br J Nutr. 2022;128(9):1720-1729. doi:10.1017/S0007114521004645 | Duplicate
1565 | Mohammadi, S, Mazloomi, SM, Niakousari, M, et al. Evaluating the effects of dark chocolate formulated with micro-encapsulated fermented garlic extract on cardio-metabolic indices in hypertensive patients: A crossover, triple-blind placebo-controlled randomized clinical trial. Phytother Res. Apr 2022;36(4):1785-1796. doi:10.1002/ptr.7421 | Intervention/Exposure
1566 | Mohammadifard, N, Nazem, M, Naderi, GA, et al. Effect of hydrogenated, liquid and ghee oils on serum lipids profile. ARYA Atheroscler. Spring 2010;6(1):16-22. | Duplicate
1567 | Mohammadifard, N, Talaei, M, Sadeghi, M, et al. Dietary patterns and mortality from cardiovascular disease: Isfahan Cohort Study. European Journal of Clinical Nutrition. 2017. 71:252-258. doi:10.1038/ejcn.2016.170 | Intervention/Exposure; No confounder adjustment
1568 | Mohammadi-Sartang, M, Bellissimo, N, Totosy de Zepetnek, JO, et al. The effect of daily fortified yogurt consumption on weight loss in adults with metabolic syndrome: A 10-week randomized controlled trial. Nutr Metab Cardiovasc Dis. 2018. 28:565-574. doi:10.1016/j.numecd.2018.03.001 | Intervention/Exposure; Comparator
1569 | Mohammadi-Sartang, M, Mazloomi, SM, Fararouie, M, et al. Daily fortified-synbiotic yogurt consumption facilitates appetite control in overweight and obese adults with metabolic syndrome during a weight-loss program: a 10-week randomized controlled trial. Progress in Nutrition. Dec 2019;21:135-144. doi:10.23751/pn.v21i2-S.6906 | Outcome; Comparator
1570 | Mokhtari, Z, Nasrollahzadeh, J, Miri, R, et al. Relationship between dietary approaches to stop hypertension score and presence or absence of coronary heart diseases in patients referring to Imam Hossein Hospital, Tehran, Iran. ARYA Atheroscler. Nov 2013;9(6):319-25. | Study design
1571 | Molinari C, Rise P, Guerra C, et al. Eight-week consumption of milk enriched with omega 3 fatty acids raises their blood concentrations yet does not affect lipids and cardiovascular disease risk factors in adult healthy volunteers. PharmaNutrition. 2014;2(4):141-148. doi: 10.1016/j.phanu.2014.06.001 | Comparator
1572 | Molitor, J, Brown, IJ, Chan, Q, et al. Blood pressure differences associated with Optimal Macronutrient Intake Trial for Heart Health (OMNIHEART)-like diet compared with a typical American Diet. Hypertension. Dec 2014;64(6):1198-204. doi:10.1161/HYPERTENSIONAHA.114.03799 | Intervention/Exposure
1573 | Møller, SP, Mejborn, H, Christensen, AI, et al. Meat consumption, stratified by dietary quality, and risk of heart disease. Br J Nutr. 2021. 126:1881-1887. doi:10.1017/s0007114521000623 | Comparator
1574 | Monagas, M, Khan, N, Andres-Lacueva, C, et al. Effect of cocoa powder on the modulation of inflammatory biomarkers in patients at high risk of cardiovascular disease. Am J Clin Nutr. 2009. 90:1144-50. doi:10.3945/ajcn.2009.27716 | Intervention/Exposure
1575 | Monfort-Pires, M, Ferreira, SR. Inflammatory and metabolic responses to dietary intervention differ among individuals at distinct cardiometabolic risk levels. Nutrition. 2017. 33:331-337. doi:10.1016/j.nut.2016.07.021 | Intervention/Exposure
1576 | Monge, A, Lajous, M, Ortiz-Panozo, E, et al. Western and Modern Mexican dietary patterns are directly associated with incident hypertension in Mexican women: a prospective follow-up study. Nutr J. 2018. 17:21. doi:10.1186/s12937-018-0332-3 | Intervention/Exposure
1577 | Monge, A, Silva Canella, D, López-Olmedo, N, et al. Ultraprocessed beverages and processed meats increase the incidence of hypertension in Mexican women. Br J Nutr. 2021. 126:600-611. doi:10.1017/s0007114520004432 | Comparator
1578 | Monge, A, Stern, D, Cortés-Valencia, A, et al. Avocado consumption is associated with a reduction in hypertension incidence in Mexican women. British Journal of Nutrition. Jun 14 2023;129(11):1976-1983. doi:Pii S0007114522002690 10.1017/S0007114522002690 | Intervention/Exposure
1579 | Montague, C, D’Angelo, S, Harvey, N, et al. Development of a measure of dietary quality for the UK Biobank. J Public Health (Oxf). Nov 29 2023;45(4):e755-e762. doi:10.1093/pubmed/fdad103 | Study design; Intervention/Exposure
1580 | Montonen, J, Järvinen, R, Reunanen, A, et al. Fish consumption and the incidence of cerebrovascular disease. Br J Nutr. 2009. 102:750-6. doi:10.1017/s0007114509274782 | Intervention/Exposure
1581 | Montoya, MT, Porres, A, Serrano, S, et al. Fatty acid saturation of the diet and plasma lipid concentrations, lipoprotein particle concentrations, and cholesterol efflux capacity. Am J Clin Nutr. Mar 2002;75(3):484-91. doi:10.1093/ajcn/75.3.484 | Intervention/Exposure
1582 | Moore, C, Gitau, R, Goff, L, et al. Successful manipulation of the quality and quantity of fat and carbohydrate consumed by free-living individuals using a food exchange model. J Nutr. Aug 2009;139(8):1534-40. doi:10.3945/jn.108.103374 | Intervention/Exposure
1583 | Moore, LL, Bradlee, ML, Singer, MR, et al. Dietary Approaches to Stop Hypertension (DASH) eating pattern and risk of elevated blood pressure in adolescent girls. Br J Nutr. Nov 14 2012;108(9):1678-85. doi:10.1017/S000711451100715X | Intervention/Exposure; Comparator
1584 | Moore, LL, Singer, MR, Bradlee, ML, et al. Adolescent dietary intakes predict cardiometabolic risk clustering. Eur J Nutr. Mar 2016;55(2):461-468. doi:10.1007/s00394-015-0863-8 | Intervention/Exposure; Outcome
1585 | Moore, LL, Singer, MR, Bradlee, ML, et al. Intake of fruits, vegetables, and dairy products in early childhood and subsequent blood pressure change. Epidemiology. Jan 2005;16(1):4-11. doi:10.1097/01.ede.0000147106.32027.3e | Intervention/Exposure; Comparator
1586 | Moore, TJ, Conlin, PR, Ard, J, et al. DASH (Dietary Approaches to Stop Hypertension) diet is effective treatment for stage 1 isolated systolic hypertension. Hypertension. Aug 2001;38(2):155-158. doi:Doi 10.1161/01.Hyp.38.2.155 | Intervention/Exposure; Sample size/Power
1587 | Moore, TJ, Vollmer, WM, Appel, LJ, et al. Effect of dietary patterns on ambulatory blood pressure : results from the Dietary Approaches to Stop Hypertension (DASH) Trial. DASH Collaborative Research Group. Hypertension. 1999. 34:472-7. doi:10.1161/01.hyp.34.3.472 | Intervention/Exposure
1588 | Moraes, Wmam, Santos, NSD, Aguiar, LP, et al. Maintenance of exercise training benefits is associated with adequate milk and dairy products intake in elderly hypertensive subjects following detraining. Einstein (Sao Paulo). 2017. 15:289-294. doi:10.1590/s1679-45082017ao4048 | Intervention/Exposure; Sample size/Power
1589 | Moreno, JA, López-Miranda, J, Pérez-Martínez, P, et al. A monounsaturated fatty acid-rich diet reduces macrophage uptake of plasma oxidised low-density lipoprotein in healthy young men. Br J Nutr. Sep 2008;100(3):569-75. doi:10.1017/S0007114508911508 | Sample size/Power
1590 | Moreno, JA, Pérez-Jiménez, F, Marín, C, et al. Apolipoprotein E gene promoter - 219G->T polymorphism increases LDL-cholesterol concentrations and susceptibility to oxidation in response to a diet rich in saturated fat. Am J Clin Nutr. 2004. 80:1404-9. doi:10.1093/ajcn/80.5.1404 | Intervention/Exposure
1591 | Moreno, JA, Pérez-Jiménez, F, Marín, C, et al. The effect of dietary fat on LDL size is influenced by apolipoprotein E genotype in healthy subjects. Journal of Nutrition. Oct 2004;134(10):2517-2522. doi:DOI 10.1093/jn/134.10.2517 | Intervention/Exposure
1592 | Moreno, LA, Bel-Serrat, S, Santaliestra-Pasías, A, et al. Dairy products, yogurt consumption, and cardiometabolic risk in children and adolescents. Nutrition Reviews. 2015. 73:8-14. doi:10.1093/nutrit/nuv014 | Study design; Outcome
1593 | Morgan JM, Tavani DM, Garwin JL, et al. Effect of dietary (egg) cholesterol on serum cholesterol in free-living adults. J Appl Nutr. 1993;45(3/4): 74-84. | Intervention/Exposure
1594 | Morgan, SA, Sinclair, AJ, O’Dea, K. Effect on serum lipids of addition of safflower oil or olive oil to very-low-fat diets rich in lean beef. J Am Diet Assoc. Jun 1993;93(6):6448. doi:10.1016/0002-8223(93)91669-h | Intervention/Exposure; Sample size/Power
1595 | Mori, TA, Vandongen, R, Beilin, LJ, et al. Effects of Varying Dietary-Fat, Fish, and Fish Oils on Blood-Lipids in a Randomized Controlled Trial in Men at Risk of Heart-Disease. American Journal of Clinical Nutrition. May 1994;59(5):1060-1068. doi:DOI 10.1093/ajcn/59.5.1060 | Intervention/Exposure
1596 | Mosca, L, Mochari, H, Liao, M, et al. A novel family-based intervention trial to improve heart health: FIT Heart: results of a randomized controlled trial. Circ Cardiovasc Qual Outcomes. Nov 2008;1(2):98-106. doi:10.1161/CIRCOUTCOMES.108.825786 | Intervention/Exposure
1597 | Moslehi, N, Rahimi Sakak, F, Mahdavi, M, et al. Visceral adiposity-related dietary patterns and the risk of cardiovascular disease in Iranian adults: A population-based cohort study. Front Nutr. 2022. 9:812701. doi:10.3389/fnut.2022.812701 | Intervention/Exposure
1598 | Most, MM, Tulley, R, Morales, S, et al. Rice bran oil, not fiber, lowers cholesterol in humans. American Journal of Clinical Nutrition. 2005. 81:64-68. doi:10.1093/ajcn/81.1.64 | Intervention/Exposure
1599 | Mostofsky, E, Levitan, EB, Wolk, A, et al. Chocolate intake and incidence of heart failure: a population-based prospective study of middle-aged and elderly women. Circ Heart Fail. Sep 2010;3(5):612-6. doi:10.1161/CIRCHEARTFAILURE.110.944025 | Comparator
1600 | Mota, MC, De-Souza, DA, Rossato, LT, et al. Dietary patterns, metabolic markers and subjective sleep measures in resident physicians. Chronobiol Int. 2013. 30:1032-41. doi:10.3109/07420528.2013.796966 | Study design; Intervention/Exposure
1601 | Motard-Bélanger, A, Charest, A, Grenier, G, et al. Study of the effect of trans fatty acids from ruminants on blood lipids and other risk factors for cardiovascular disease. Am J Clin Nutr. Mar 2008;87(3):593-9. doi:10.1093/ajcn/87.3.593 | Intervention/Exposure
1602 | Mott, MM, McCrory, MA, Bandini, LG, et al. Egg Intake Has No Adverse Association With Blood Lipids Or Glucose In Adolescent Girls. J Am Coll Nutr. 2019. 38:119-124. doi:10.1080/07315724.2018.1469437 | Intervention/Exposure
1603 | Mougios, V, Matsakas, A, Petridou, A, et al. Effect of supplementation with conjugated linoleic acid on human serum lipids and body fat. J Nutr Biochem. Oct 2001;12(10):585-594. doi:10.1016/s0955-2863(01)00177-2 | Intervention/Exposure; Sample size/Power
1604 | Moy, FM, Ab Sallam, A, Wong, ML. Dietary modification in a workplace health promotion program in Kuala Lumpur, Malaysia. Asia Pac J Public Health. Oct 2008;20 Suppl:166-72. | Intervention/Exposure
1605 | Mozaffarian, D. Diverging global trends in heart disease and type 2 diabetes: the role of carbohydrates and saturated fats. Lancet Diabetes Endocrinol. Aug 2015;3(8):586-8. doi:10.1016/S2213-8587(15)00208-9 | Study design
1606 | Mozaffarian, D. The great fat debate: taking the focus off of saturated fat. J Am Diet Assoc. May 2011;111(5):665-6. doi:10.1016/j.jada.2011.03.030 | Study design
1607 | Mraz, J, Zajic, T, Kozak, P, et al. Intake of Carp Meat From Two Aquaculture Production Systems Aimed at Secondary Prevention of Ischemic Heart Disease a Follow-up Study. Physiological Research. 2017;66:S129-S137. doi:10.33549/physiolres.933586 | Intervention/Exposure; Health status
1608 | Mrázová, J, Gažarová, M, Kopčeková, J, et al. The effect of consumption of pork enriched by organic selenium on selenium status and lipid profile in blood serum of consumers. J Environ Sci Health B. 2020;55(1):69-74. doi:10.1080/03601234.2019.1653734 | Comparator; Sample size/Power
1609 | Mrázová, J, Kopčeková, J, Debrecéni, O, et al. Effect of short-term consumption of pork supplemented by organic selenium on selenium concentration, antioxidant status, and lipid parameters of consumers. J Environ Sci Health B. 2021;56(10):884-890. doi:10.1080/03601234.2021.1973323 | Intervention/Exposure; Comparator
1610 | Muhammad Ismail Tadj, NB, Ibrahim, NI, Tg Abu Bakar Sidik, TMI, et al. Safety and efficacy of oil palm phenolic supplementation in improving lipid profile among hyperlipidemic adults: a phase 2, randomized, double-blind, placebo-controlled clinical trial. Front Pharmacol. 2023. 14:1190663. doi:10.3389/fphar.2023.1190663 | Comparator; Sample size/Power
1611 | Muka, T, Blekkenhorst, LC, Lewis, JR, et al. Dietary fat composition, total body fat and regional body fat distribution in two Caucasian populations of middle-aged and older adult women. Clin Nutr. Oct 2017;36(5):1411-1419. doi:10.1016/j.clnu.2016.09.018 | Intervention/Exposure
1612 | Mukherjee, S. In nonalcoholic fatty liver disease, a diet of freshwater fish vs. freshwater fish plus red meat reduced liver fat. Ann Intern Med. Feb 2023;176(2):JC20. doi:10.7326/J22-0117 | Study design; Publication status
1613 | Müller, H, Jordal, O, Kierulf, P, et al. Replacement of partially hydrogenated soybean oil by palm oil in margarine without unfavorable effects on serum lipoproteins. Lipids. 1998. 33:879-87. doi:10.1007/s11745-998-0284-9 | Duration; Sample size/Power
1614 | Munisekhar, K, Singh, Sb M, Rao, PS, et al. Lipid profile in healthy human volunteers before and after consuming ghee. Bioinformation. 2022. 18:742-747. doi:10.6026/97320630018742 | Study design; Country
1615 | Muñoz-Perez, DM, Gonzalez-Correa, CH, Astudillo-Muñoz, EY, et al. Alternative Foods in Cardio-Healthy Dietary Models That Improve Postprandial Lipemia and Insulinemia in Obese People. Nutrients. 2021. 13:2225. doi:10.3390/nu13072225 | Intervention/Exposure
1616 | Murphy, B, Talegawkar, SA, O’Connor, J, et al. Association between dairy product intake and body composition among South Asian adults from the Mediators of Atherosclerosis in South Asians Living in America (MASALA) study. British Journal of Nutrition. Oct 14 2021;126(7):1100-1109. doi:Pii S000711452000506110.1017/S0007114520005061 | Outcome
1617 | Murphy, KJ, Thomson, RL, Coates, AM, et al. Effects of eating fresh lean pork on cardiometabolic health parameters. Nutrients. 2012. 4:711-23. doi:10.3390/nu4070711 | Intervention/Exposure; Comparator
1618 | Musicus, AA, Wang, DD, Janiszewski, M, et al. Health and environmental impacts of plant-rich dietary patterns: a US prospective cohort study. The Lancet Planetary Health. 2022. 6:e892-e900. doi:10.1016/S2542-5196(22)00243-1 | Intervention/Exposure
1619 | Mustad, VA, Etherton, TD, Cooper, AD, et al. Reducing saturated fat intake is associated with increased levels of LDL receptors on mononuclear cells in healthy men and women. Journal of Lipid Research. Mar 1997;38(3):459-468. | Intervention/Exposure; Sample size/Power
1620 | Mutalib, MSA, Khaza’ai, H, Peace, H, et al. Palm oil-enriched diets reduced plasma Lp(a) in volunteers with abnormally high concentrations: involvement of decreased triglyceride-rich APO(a). Nutrition Research. Jul 2002;22(7):769-784. doi:Pii S0271-5317(02)00379-2 Doi 10.1016/S0271-5317(02)00379-2 | Study design
1621 | Mutalib, MSA, Wahle, KWJ, Duthie, GG, et al. The effect of dietary palm oil, hydrogenated rape and soya oil on indices of coronary heart disease risk in healthy Scottish volunteers. Nutrition Research. Mar 1999;19(3):335-348. doi:Doi 10.1016/S0271-5317(99)00003-2 | Sample size/Power
1622 | Mutanen M, Freese R, Valsta LM, Ahola I, Ahlström A. Rapeseed oil and sunflower oil diets enhance platelet in vitro aggregation and thromboxane production in healthy men when compared with milk fat or habitual diets. Thromb Haemost. 1992;67(3):352-356. | Duration; Sample size/Power
1623 | Mutanen, M, Aro, A. Coagulation and fibrinolysis factors in healthy subjects consuming high stearic or trans fatty acid diets. Thromb Haemost. Jan 1997;77(1):99-104. | Intervention/Exposure
1624 | Mytton, OT, Forouhi, NG, Scarborough, P, et al. Association between intake of lesshealthy foods defined by the United Kingdom’s nutrient profile model and cardiovascular disease: A population-based cohort study. PLoS Med. 2018. 15:e1002484. doi:10.1371/journal.pmed.1002484 | Intervention/Exposure
1625 | Na, L, Han, T, Zhang, W, et al. A Snack Dietary Pattern Increases the Risk of Hypercholesterolemia in Northern Chinese Adults: A Prospective Cohort Study. PLoS One. 2015. 10:e0134294. doi:10.1371/journal.pone.0134294 | Intervention/Exposure
1626 | Nagao, M, Iso, H, Yamagishi, K, et al. Meat consumption in relation to mortality from cardiovascular disease among Japanese men and women. European Journal of Clinical Nutrition. Jun 2012;66(6):687-693. doi:10.1038/ejcn.2012.6 | Comparator
1627 | Nagashree, RS, Manjunath, NK, Indu, M, et al. Effect of a Diet Enriched with Fresh Coconut Saturated Fats on Plasma Lipids and Erythrocyte Fatty Acid Composition in Normal Adults. J Am Coll Nutr. Jul 2017;36(5):330-334. doi:10.1080/07315724.2017.1280713 | Country
1628 | Nagata, C, Nakamura, K, Wada, K, et al. Total fat intake is associated with decreased mortality in Japanese men but not in women. J Nutr. 2012. 142:1713-9. doi:10.3945/jn.112.161661 | Intervention/Exposure
1629 | Nagaya, T, Nakaya -i, K, Takahashi, A, et al. Relationships between Serum Saturated Fatty-Acids and Serum Total Cholesterol and Hdl-Cholesterol in Humans. Annals of Clinical Biochemistry. May 1994;31:240-244. doi:Doi 10.1177/000456329403100304 | Intervention/Exposure
1630 | Nagyova, A, Haban, P, Klvanova, J, et al. Effects of dietary extra virgin olive oil on serum lipid resistance to oxidation and fatty acid composition in elderly lipidemic patients. Bratisl Lek Listy. 2003;104(7-8):218-21. | Study design; Intervention/Exposure
1631 | Naito, C. The effect of milk intake on serum cholesterol in healthy young females. Randomized controlled studies. Ann N Y Acad Sci. 1990;598:482-90. doi:10.1111/j.1749-6632.1990.tb42318.x | Sample size/Power
1632 | Nakamura Y, Kiyohara Y, Okuda N, et al. Fatty acid intakes and coronary heart disease mortality in Japan: NIPPON DATA90, 1990-2005. Current Nutrition and Food Science. 2013;9(1):26-32. | Intervention/Exposure
1633 | Nakamura, T, Azuma, A, Kuribayashi, T, et al. Serum fatty acid levels, dietary style and coronary heart disease in three neighbouring areas in Japan: the Kumihama study. Br J Nutr. Feb 2003;89(2):267-72. doi:10.1079/BJN2002747 | Intervention/Exposure
1634 | Nakamura, Y, Okuda, N, Okamura, T, et al. Low-carbohydrate diets and cardiovascular and total mortality in Japanese: A 29-year follow-up of NIPPON DATA80. British Journal of Nutrition. 2014. 112:916-924. doi:10.1017/S0007114514001627 | Intervention/Exposure
1635 | Nakamura, Y, Ueshima, H, Okuda, N, et al. Relationship of three different types of low-carbohydrate diet to cardiometabolic risk factors in a Japanese population: the INTERMAP/INTERLIPID Study. Eur J Nutr. Jun 2016;55(4):1515-24. doi:10.1007/s00394-015-0969-z | Intervention/Exposure
1636 | Namayandeh, SM, Kaseb, F, Lesan, S. Olive and sesame oil effect on lipid profile in hypercholesterolemic patients, which better? Article. International Journal of Preventive Medicine. 2013;4(9):1059-1062. | Intervention/Exposure
1637 | Nanri, A, Mizoue, T, Shimazu, T, et al. Dietary patterns and all-cause, cancer, and cardiovascular disease mortality in Japanese men and women: The Japan public health center-based prospective study. PLoS One. 2017. 12:e0174848. doi:10.1371/journal.pone.0174848 | Intervention/Exposure
1638 | Naomi, ND, Brouwer-Brolsma, EM, Buso, MEC, et al. Association of sweetened beverages consumption with all-cause mortality risk among Dutch adults: the Lifelines Cohort Study (the SWEET project). European Journal of Nutrition. 2023. 62:797-806. doi:10.1007/s00394-022-03023-6 | Intervention/Exposure; Comparator
1639 | Nasrollahzadeh, J, Khandouzi, N, Maroofi, M. Effect of a Reduced-Calorie Diet on Plasma Levels of Inflammatory and Metabolic Factors in Overweight/Obese Patients with Cardiovascular Risk Factors. Int J Endocrinol Metab. Apr 2023;21(2):e135216. doi:10.5812/ijem-135216 | Intervention/Exposure
1640 | Nasser, R, Cook, SL, Dorsch, KD, et al. Comparison of two nutrition education approaches to reduce dietary fat intake and serum lipids reveals registered dietitians are effective at disseminating information regardless of the educational approach. Journal of the American Dietetic Association. Jun 2006;106(6):850-859. doi:10.1016/j.jada.2006.03.011 | Intervention/Exposure
1641 | Navas-Carretero, S, Pérez-Granados, AM, Schoppen, S, et al. An oily fish diet increases insulin sensitivity compared to a red meat diet in young iron-deficient women. Br J Nutr. 2009. 102:546-53. doi:10.1017/s0007114509220794 | Sample size/Power
1642 | Navas-Carretero, S, Pérez-Granados, AM, Schoppen, S, et al. Iron status biomarkers in iron deficient women consuming oily fish versus red meat diet. J Physiol Biochem. Jun 2009;65(2):165-74. doi:10.1007/BF03179067 | Sample size/Power
1643 | Nazari, SSH, Mokhayeri, Y, Mansournia, MA, et al. Associations between dietary risk factors and ischemic stroke: a comparison of regression methods using data from the Multi-Ethnic Study of Atherosclerosis. Epidemiol Health. 2018. 40:e2018021. doi:10.4178/epih.e2018021 | Intervention/Exposure; Country
1644 | Nct, . A Randomized, Controlled, Trial to Assess the Effects of Low-fat Dairy Intake on Endothelial Function and Blood Pressure in Subjects With Pre-hypertension or Stage 1 Hypertension. https://clinicaltrials.gov/study/NCT01463085 | Publication status
1645 | Nct, . Effect of Different Dosages of Dark Chocolate on Arterial Blood Pressure in Cardiovascular High-risk Patients. https://clinicaltrials.gov/study/NCT01463085 | Publication status
1646 | Nct, . Effects of Hard Cheese and Butter on Markers of Cardiovascular Disease -A Randomized Controlled Dietary Human Intervention. https://clinicaltrials.gov/study/NCT01140165 | Publication status
1647 | Nct, . LACTOPRES: study on the Effect of Dairy Peptides on Blood Pressure in Untreated Hypertensive Subjects. https://clinicaltrials.gov/study/NCT00167869 | Publication status
1648 | Nct, . Randomized Controlled, Parallel Group, Single Blinded, Phase 1 Study That Investigates the Effects of Regular Daily Intake of Small Amounts of Dark or White Chocolate on Blood Pressure in Elderly Individuals With Mild Hypertension. https://clinicaltrials.gov/study/NCT00421499 | Publication status
1649 | Nct, . Study of the Impact of Trans Fatty Acids From Dairy Products n Cardiovascular Risk Factors. https://clinicaltrials.gov/study/NCT01163175 | Publication status
1650 | Nct, . The Effects of Dark Chocolate on Blood Pressure in Mildly Hypertensive Individuals. https://clinicaltrials.gov/study/NCT02130141 | Publication status
1651 | Neelakantan, N, Koh, WP, Yuan, JM, et al. Diet-Quality Indexes Are Associated with a Lower Risk of Cardiovascular, Respiratory, and All-Cause Mortality among Chinese Adults. J Nutr. 2018. 148:1323-1332. doi:10.1093/jn/nxy094 | Comparator
1652 | Nelson GJ, Schmidt PC, Kelley DS. Low-fat diets do not lower plasma cholesterol levels in healthy men compared to high-fat diets with similar fatty acid composition at constant caloric intake. Lipids. 1995;30(11):969-976. doi:10.1007/BF02536280 | Intervention/Exposure
1653 | Nelson, GJ, Schmidt, PC, Corash, L. The effect of a salmon diet on blood clotting, platelet aggregation and fatty acids in normal adult men. Lipids. Feb 1991;26(2):87-96. doi:10.1007/BF02544000 | Intervention/Exposure; Sample size/Power
1654 | Nenseter, MS, Volden, V, Tonstad, S, et al. Modification of low density lipoprotein in relation to intake of fatty acids and antioxidants. World Rev Nutr Diet. 1994;75:144-8. doi:10.1159/000423570 | Study design; Intervention/Exposure; Sample size/Power
1655 | Ness, AR, Davey Smith, G, Hart, C. Milk, coronary heart disease and mortality. Journal of Epidemiology and Community Health. 2001. 55:379-382. doi:10.1136/jech.55.6.379 | Comparator
1656 | Ness, AR, Maynard, M, Frankel, S, et al. Diet in childhood and adult cardiovascular and all cause mortality: the Boyd Orr cohort. Heart. 2005. 91:894-8. doi:10.1136/hrt.2004.043489 | Intervention/Exposure
1657 | Nestel, P, Cehun, M, Pomeroy, S, et al. Cholesterol-lowering effects of plant sterol esters and non-esterified stanols in margarine, butter and low-fat foods. Eur J Clin Nutr. 2001. 55:1084-90. doi:10.1038/sj.ejcn.1601264 | Intervention/Exposure; Sample size/Power
1658 | Nestel, P, Noakes, M, Belling, B, et al. Plasma lipoprotein lipid and Lp[a] changes with substitution of elaidic acid for oleic acid in the diet. J Lipid Res. Jul 1992;33(7):1029-36. | Duration; Sample size/Power
1659 | Nestel, PJ, Baghurst, K, Colquhoun, DM, et al. Relation of diet to cardiovascular disease risk factors in subjects with cardiovascular disease in Australia and New Zealand: analysis of the Long-Term Intervention with Pravastatin in Ischaemic Disease trial. Am J Clin Nutr. 2005. 81:1322-9. doi:10.1093/ajcn/81.6.1322 | Intervention/Exposure; Health status
1660 | Nestel, PJ, Mellett, N, Pally, S, et al. Effects of low-fat or full-fat fermented and non-fermented dairy foods on selected cardiovascular biomarkers in overweight adults. Br J Nutr. 2013. 110:2242-9. doi:10.1017/s0007114513001621 | Duration
1661 | Nestel, PJ, Pomeroy, S, Kay, S, et al. Effect of a stearic acid-rich, structured triacylglycerol on plasma lipid concentrations. Am J Clin Nutr. 1998. 68:1196-201. doi:10.1093/ajcn/68.6.1196 | Sample size/Power
1662 | Nettleton, JA, Brouwer, IA, Geleijnse, JM, et al. Saturated Fat Consumption and Risk of Coronary Heart Disease and Ischemic Stroke: A Science Update. Ann Nutr Metab. 2017;70(1):26-33. doi:10.1159/000455681 | Study design
1663 | Nettleton, JA, Polak, JF, Tracy, R, et al. Dietary patterns and incident cardiovascular disease in the Multi-Ethnic Study of Atherosclerosis. Am J Clin Nutr. 2009. 90:647-54. doi:10.3945/ajcn.2009.27597 | Intervention/Exposure
1664 | Nettleton, JA, Schulze, MB, Jiang, R, et al. A priori-defined dietary patterns and markers of cardiovascular disease risk in the Multi-Ethnic Study of Atherosclerosis (MESA). Am J Clin Nutr. 2008. 88:185-94. doi:10.1093/ajcn/88.1.185 | Intervention/Exposure
1665 | Nettleton, JA, Steffen, LM, Loehr, LR, et al. Incident heart failure is associated with lower whole-grain intake and greater high-fat dairy and egg intake in the Atherosclerosis Risk in Communities (ARIC) study. J Am Diet Assoc. 2008. 108:1881-7. doi:10.1016/j.jada.2008.08.015 | Comparator
1666 | Nettleton, JA, Steffen, LM, Ni, H, et al. Dietary patterns and risk of incident type 2 diabetes in the Multi-Ethnic Study of Atherosclerosis (MESA). Diabetes Care. 2008. 31:1777-82. doi:10.2337/dc08-0760 | Intervention/Exposure; Outcome
1667 | Nettleton, JA, Steffen, LM, Schulze, MB, et al. Associations between markers of subclinical atherosclerosis and dietary patterns derived by principal components analysis and reduced rank regression in the Multi-Ethnic Study of Atherosclerosis (MESA). Am J Clin Nutr. 2007. 85:1615-25. doi:10.1093/ajcn/85.6.1615 | Study design; Intervention/Exposure
1668 | Neuhouser, ML, Howard, B, Lu, J, et al. A low-fat dietary pattern and risk of metabolic syndrome in postmenopausal women: the Women’s Health Initiative. Metabolism. 2012. 61:1572-81. doi:10.1016/j.metabol.2012.04.007 | Intervention/Exposure
1669 | Ng, TK, Hassan, K, Lim, JB, et al. Nonhypercholesterolemic effects of a palm-oil diet in Malaysian volunteers. Am J Clin Nutr. Apr 1991;53(4 Suppl):1015S-1020S. doi:10.1093/ajcn/53.4.1015S | Sample size/Power
1670 | Ng, TK, Hayes, KC, DeWitt, GF, et al. Dietary palmitic and oleic acids exert similar effects on serum cholesterol and lipoprotein profiles in normocholesterolemic men and women. J Am Coll Nutr. 1992. 11:383-90. doi:10.1080/07315724.1992.10718241 | Country
1671 | Ngai, C, Ganguzza, L, Flink, L, et al. Comparison of Dietary Patterns, Perceptions of Health, and Perceived Barriers to a Heart Healthy Diet Before and After Coronary Artery Angiography. American Journal of Cardiology. 2019. 123:865-873. doi:10.1016/j.amjcard.2018.11.056 | Intervention/Exposure; Health status
1672 | Nguyen, HD, Oh, H, Kim, MS. Higher intakes of fruits, vegetables, and multiple individual nutrients is associated with a lower risk of metabolic syndrome among adults with comorbidities. Nutrition Research. Mar 2022;99:1-12. doi:10.1016/j.nutres.2021.11.004 | Intervention/Exposure; Outcome
1673 | Nicholl, A, Deering, KE, Evelegh, K, et al. Whole-fat dairy products do not adversely affect adiposity or cardiometabolic risk factors in children in the Milky Way Study: A double-blind randomized controlled pilot study. American Journal of Clinical Nutrition. 2021. 114:2025-2042. doi:10.1093/ajcn/nqab288 | Sample size/Power
1674 | Nicklas, TA, Dwyer, J, Feldman, HA, et al. Serum cholesterol levels in children are associated with dietary fat and fatty acid intake. J Am Diet Assoc. Apr 2002;102(4):511-7. doi:10.1016/s0002-8223(02)90117-3 | Intervention/Exposure
1675 | Nicklas, TA. Avoidance of dairy products: implications for nutrient adequacy and health. Can Nurse. Sep 2012;108(7):1 p following toc. | Study design
1676 | Nicol, K, Mansoorian, B, Latosinska, A, et al. No evidence of differential impact of sunflower and rapeseed oil on biomarkers of coronary artery disease or chronic kidney disease in healthy adults with overweight and obesity: result from a randomised control trial. European Journal of Nutrition. 2022. 61:3119-3133. doi:10.1007/s00394-022-02810-5 | Intervention/Exposure; Sample size/Power
1677 | Nigon, F, Serfaty-Lacrosnière, C, Beucler, I, et al. Plant sterol-enriched margarine lowers plasma LDL in hyperlipidemic subjects with low cholesterol intake: effect of fibrate treatment. Clin Chem Lab Med. Jul 2001;39(7):634-40. doi:10.1515/CCLM.2001.103 | Intervention/Exposure; Comparator
1678 | Niinikoski, H, Jula, A, Viikari, J, et al. Blood Pressure Is Lower in Children and Adolescents With a Low-Saturated-Fat Diet Since Infancy The Special Turku Coronary Risk Factor Intervention Project. Hypertension. Jun 2009;53(6):918-924. doi:10.1161/Hypertensionaha.109.130146 | Intervention/Exposure
1679 | Niinikoski, H, Lagström, H, Jokinen, E, et al. Impact of repeated dietary Counseling between infancy and 14 years of age on dietary intakes and serum lipids and lipoproteins -: The STRIP study. Circulation. Aug 28 2007;116(9):1032-1040. doi:10.1161/Circulationaha.107.699447 | Intervention/Exposure; Population
1680 | Niinikoski, H, Pahkala, K, Ala-Korpela, M, et al. Effect of repeated dietary counseling on serum lipoproteins from infancy to adulthood. Pediatrics. Mar 2012;129(3):e704-13. doi:10.1542/peds.2011-1503 | Intervention/Exposure
1681 | Niinikoski, H, Pahkala, K, Viikari, J, et al. The STRIP Study: Long-Term Impact of a Low Saturated Fat/Low Cholesterol Diet. Current Cardiovascular Risk Reports. Nov 2014;8(11)doi:ARTN 410 10.1007/s12170-014-0410-9 | Intervention/Exposure; Population
1682 | Nikolic, M, Ristic Medic, D, Stanic, D, et al. Dietary lipid intake influences the level of cholesterol bound to haemoglobin in human erythrocytes. Eur J Nutr. Apr 2008;47(3):123-30. doi:10.1007/s00394-008-0705-z | Intervention/Exposure; Sample size/Power
1683 | Nikooei, P, Hosseinzadeh-Attar, MJ, Asghari, S, et al. Effects of virgin coconut oil consumption on metabolic syndrome components and asymmetric dimethylarginine: A randomized controlled clinical trial. Nutr Metab Cardiovasc Dis. 2021. 31:939-949. doi:10.1016/j.numecd.2020.11.020 | Sample size/Power
1684 | Nilsen, R, Pripp, AH, Høstmark, AT, et al. Effect of a cheese rich in angiotensin-converting enzyme-inhibiting peptides (Gamalost(®)) and a Gouda-type cheese on blood pressure: results of a randomised trial. Food Nutr Res. 2016. 60:32017. doi:10.3402/fnr.v60.32017 | Comparator
1685 | Nilsson, LM, Winkvist, A, Brustad, M, et al. A traditional Sami diet score as a determinant of mortality in a general northern Swedish population. Int J Circumpolar Health. 2012. 71:1-12. doi:10.3402/ijch.v71i0.18537 | Outcome
1686 | Nilsson, LM, Winkvist, A, Eliasson, M, et al. Low-carbohydrate, high-protein score and mortality in a northern Swedish population-based cohort. Eur J Clin Nutr. 2012. 66:694-700. doi:10.1038/ejcn.2012.9 | Intervention/Exposure
1687 | Nishiwaki, M, Nakano, Y, Matsumoto, N. Effects of regular high-cocoa chocolate intake on arterial stiffness and metabolic characteristics during exercise. Nutrition. 2019. 60:53-58. doi:10.1016/j.nut.2018.09.021 | Comparator
1688 | Niswender, KD, Fazio, S, Gower, BA, et al. Balanced high fat diet reduces cardiovascular risk in obese women although changes in adipose tissue, lipoproteins, and insulin resistance differ by race. Metabolism-Clinical and Experimental. May 2018;82:125-134. doi:10.1016/j.metabol.2018.01.020 | Intervention/Exposure
1689 | Njembe, MTN, Pachikian, B, Lobysheva, I, et al. A Three-Month Consumption of Eggs Enriched with ω-3, ω-5 and ω-7 Polyunsaturated Fatty Acids Significantly Decreases the Waist Circumference of Subjects at Risk of Developing Metabolic Syndrome: A Double-Blind Randomized Controlled Trial. Nutrients. Feb 2021;13(2)doi:ARTN 663 10.3390/nu13020663 | Intervention/Exposure; Sample size/Power
1690 | Njike, V, Faridi, Z, Dutta, S, et al. Daily egg consumption in hyperlipidemic adults-effects on endothelial function and cardiovascular risk. Nutr J. 2010. 9:28. doi:10.1186/1475-2891-9-28 | Intervention/Exposure
1691 | Njike, VY, Kela, GCM, Treu, JA, et al. Egg Consumption in the Context of Plant-Based Diets and Diet Quality in Adults at Risk for Type 2 Diabetes: A Randomized Single Blind Cross-over Controlled Trial. Journal of the American Nutrition Association. Feb 17 2023;42(2):130-139. doi:10.1080/07315724.2021.2006824 | Intervention/Exposure
1692 | Noakes M, Nestel PJ, Clifton PM. Commercial frying fats and plasma lipid-lowering potential. Austral J Nutr Diet. 1996;53:25-30. | Duration; Sample size/Power
1693 | Noakes, M, Clifton, PM, Doornbos, AM, et al. Plant sterol ester-enriched milk and yoghurt effectively reduce serum cholesterol in modestly hypercholesterolemic subjects. Eur J Nutr. 2005. 44:214-22. doi:10.1007/s00394-004-0513-z | Health status; Duration
1694 | Noakes, M, Clifton, PM. Changes in plasma lipids and other cardiovascular risk factors during 3 energy-restricted diets differing in total fat and fatty acid composition. Am J Clin Nutr. Mar 2000;71(3):706-12. doi:10.1093/ajcn/71.3.706 | Intervention/Exposure; Sample size/Power
1695 | Noakes, M, Foster, PR, Keogh, JB, et al. Comparison of isocaloric very low carbohydrate/high saturated fat and high carbohydrate/low saturated fat diets on body composition and cardiovascular risk. Nutr Metab (Lond). 2006. 3:7. doi:10.1186/1743-7075-3-7 | Intervention/Exposure
1696 | Noakes, M, Keogh, JB, Foster, PR, et al. Effect of an energy-restricted, high-protein, low-fat diet relative to a conventional high-carbohydrate, low-fat diet on weight loss, body composition, nutritional status, and markers of cardiovascular health in obese women. Am J Clin Nutr. 2005. 81:1298-306. doi:10.1093/ajcn/81.6.1298 | Intervention/Exposure
1697 | Noakes, M, Nestel, PJ, Clifton, PM. Modifying the fatty acid profile of dairy products through feedlot technology lowers plasma cholesterol of humans consuming the products. American Journal of Clinical Nutrition. Jan 1996;63(1):42-46. doi:DOI 10.1093/ajcn/63.1.42 | Intervention/Exposure; Duration
1698 | Nobbs, HM, Yaxley, A, Thomas, J, et al. Do dietary patterns in older age influence the development of cancer and cardiovascular disease: A longitudinal study of ageing. Clin Nutr. 2016. 35:528-535. doi:10.1016/j.clnu.2015.04.003 | Intervention/Exposure
1699 | Nobmann ED, Ebbesson SO, White RG, Bulkow LR, Schraer CD. Associations between dietary factors and plasma lipids related to cardiovascular disease among Siberian Yupiks of Alaska. Int J Circumpolar Health. 1999;58(4):254-271. | Study design; Intervention/Exposure
1700 | Noel, SE, Newby, PK, Ordovas, JM, et al. A Traditional Rice and Beans Pattern Is Associated with Metabolic Syndrome in Puerto Rican Older Adults. Journal of Nutrition. Jul 2009;139(7):1360-1367. doi:10.3945/jn.109.105874 | Intervention/Exposure
1701 | Nogay, NH, Koksal, G. Effect of lifestyle on metabolic syndrome in Turkish children and adolescents. Pakistan Journal of Medical Sciences. Jul-Sep 2012;28(4):652-656. | Intervention/Exposure
1702 | Noites, A, Pinto, J, Freitas, CP, et al. Effects of the Mediterranean diet and exercise in subjects with coronary artery disease. Rev Port Cardiol. 2015. 34:655-64. doi:10.1016/j.repc.2015.05.004 | Health status; Publication language
1703 | Nourieh, Z, Keshavarz, SA, Attar, MJH, et al. Effects of soy milk consumption on inflammatory markers and lipid profiles among non-menopausal overweight and obese female adults. Journal of Research in Medical Sciences. Mar 2012;17:S65-S72. | Publication status; Sample size/Power
1704 | Noury-Desvaux, B, Congnard, F, Quertier, B, et al. Evaluation of short food-frequency questionnaires to assess the dietary pattern associated with atherosclerotic cardiovascular diseases. Design Studies. 2018. 43:283-287. doi:10.1016/j.jdmv.2018.06.003 | Intervention/Exposure; Outcome
1705 | Nowalk MP, Kuller LH, Caggiula AW. Consumption of low-fat and low-calcium diets among healthy premenopausal women. Journal of Women’s Health. 1995;4(1):35-44. | Intervention/Exposure
1706 | Nowson CA, Worsley T, Margerison C, et al. Dietary approaches to reduce blood pressure in a community setting: a randomised crossover study. Asia Pacific Journal of Clinical Nutrition. 2003;12:49. | Publication status
1707 | Nowson, CA, Wattanapenpaiboon, N, Pachett, A. Low-sodium Dietary Approaches to Stop Hypertension-type diet including lean red meat lowers blood pressure in postmenopausal women. Nutr Res. 2009. 29:8-18. doi:10.1016/j.nutres.2008.12.002 | Intervention/Exposure
1708 | Nowson, CA, Worsley, A, Margerison, C, et al. Blood pressure change with weight loss is affected by diet type in men. Am J Clin Nutr. 2005. 81:983-9. doi:10.1093/ajcn/81.5.983 | Intervention/Exposure
1709 | Nowson, CA, Worsley, A, Margerison, C, et al. Blood pressure response to dietary modifications in free-living individuals. J Nutr. 2004. 134:2322-9. doi:10.1093/jn/134.9.2322 | Intervention/Exposure; Sample size/Power
1710 | Nunes, JC, Silva, Mnlrd, Perrone, D, et al. Seasonal Variation in Fat Quality and Conjugated Linoleic Acid Content of Dairy Products from the Tropics: Evidence of Potential Impact on Human Health. Foods. Aug 1 2017;6(8)doi:10.3390/foods6080061 | Study design; Intervention/Exposure
1711 | Nuotio, IO, Raitakari, OT, Porkka, KV, et al. Associations between diet and the hyperapobetalipoproteinemia phenotype expression in children and young adults - The Cardiovascular Risk in Young Finns Study. Arteriosclerosis Thrombosis and Vascular Biology. May 1997;17(5):820-825. doi:Doi 10.1161/01.Atv.17.5.820 | Intervention/Exposure
1712 | Nuotio, P, Lankinen, M, Meuronen, T, et al. Impact of Dietary N-3 and N-6 Polyunsaturated Fatty Acids on Serum Lipoprotein(a). Atherosclerosis. Aug 2023;379:S51-S52. | Study design; Intervention/Exposure
1713 | Nupponen, M, Pahkala, K, Juonala, M, et al. Metabolic syndrome from adolescence to early adulthood: effect of infancy-onset dietary counseling of low saturated fat: the Special Turku Coronary Risk Factor Intervention Project (STRIP). Circulation. Feb 17 2015;131(7):605-13. doi:10.1161/CIRCULATIONAHA.114.010532 | Intervention/Exposure; Population
1714 | Nydahl, M, Gustafsson, IB, Ohrvall, M, et al. Similar serum lipoprotein cholesterol concentrations in healthy subjects on diets enriched with rapeseed and with sunflower oil. Eur J Clin Nutr. Feb 1994;48(2):128-37. | Duration
1715 | Oba, S, Nagata, C, Nakamura, K, et al. Diet based on the Japanese Food Guide Spinning Top and subsequent mortality among men and women in a general Japanese population. J Am Diet Assoc. 2009. 109:1540-7. doi:10.1016/j.jada.2009.06.367 | Intervention/Exposure
1716 | Obarzanek, E, Kimm, SY, Barton, BA, et al. Long-term safety and efficacy of a cholesterol-lowering diet in children with elevated low-density lipoprotein cholesterol: seven-year results of the Dietary Intervention Study in Children (DISC). Pediatrics. Feb 2001;107(2):256-64. doi:10.1542/peds.107.2.256 | Intervention/Exposure
1717 | Obarzanek, E, Sacks, FM, Vollmer, WM, et al. Effects on blood lipids of a blood pressure-lowering diet: the Dietary Approaches to Stop Hypertension (DASH) Trial. Am J Clin Nutr. Jul 2001;74(1):80-9. doi:10.1093/ajcn/74.1.80 | Intervention/Exposure
1718 | O’Callaghan, D, Stanton, A, Rafferty, S, et al. Are butter and cheese rich in monounsaturates beneficial in hyperlipidaemic patients? J Cardiovasc Risk. Oct 1996;3(5):441-5. doi:10.1177/174182679600300505 | Sample size/Power
1719 | Ockene, IS, Hebert, JR, Ockene, JK, et al. Effect of physician-delivered nutrition counseling training and an office-support program on saturated fat intake, weight, and serum lipid measurements in a hyperlipidemic population: Worcester Area Trial for Counseling in Hyperlipidemia (WATCH). Arch Intern Med. Apr 12 1999;159(7):725-31. doi:10.1001/archinte.159.7.725 | Intervention/Exposure
1720 | O’Connor LE, Li J, Sayer RD, Hennessy JE, Campbell WW. Short-Term Effects of Healthy Eating Pattern Cycling on Cardiovascular Disease Risk Factors: Pooled Results from Two Randomized Controlled Trials. Nutrients. 2018;10(11):1725. Published 2018 Nov 10. doi:10.3390/nu10111725 | Intervention/Exposure
1721 | O’Connor, A, Feeney, EL, Bhargava, N, et al. Determination of factors associated with serum cholesterol response to dairy fat consumption in overweight adults: Secondary analysis from an RCT. Front Nutr. 2022. 9:945723. doi:10.3389/fnut.2022.945723 | Intervention/Exposure
1722 | O’Connor, LM, Lentjes, MA, Luben, RN, et al. Dietary dairy product intake and incident type 2 diabetes: a prospective study using dietary data from a 7-day food diary. Diabetologia. 2014. 57:909-17. doi:10.1007/s00125-014-3176-1 | Outcome
1723 | O’Dea K, Traianedes K, Chisholm K, Leyden H, Sinclair AJ. Cholesterol-lowering effect of a low-fat diet containing lean beef is reversed by the addition of beef fat. Am J Clin Nutr. 1990;52(3):491-494. doi:10.1093/ajcn/52.3.491 | Sample size/Power
1724 | Odegaard, AO, Koh, WP, Yuan, JM, et al. Dietary patterns and mortality in a Chinese population. Am J Clin Nutr. 2014. 100:877-83. doi:10.3945/ajcn.114.086124 | Intervention/Exposure
1725 | Ogilvie, RP, Lutsey, PL, Heiss, G, et al. Dietary intake and peripheral arterial disease incidence in middle-aged adults: the Atherosclerosis Risk in Communities (ARIC) Study. Am J Clin Nutr. 2017. 105:651-659. doi:10.3945/ajcn.116.137497 | Comparator
1726 | Oh SM, Kim HC, Ahn SV, Chi HJ, Suh I. Association between meat consumption and carotid intima-media thickness in Korean adults with metabolic syndrome. J Prev Med Public Health. 2010;43(6):486-495. doi:10.3961/jpmph.2010.43.6.486 | Study design
1727 | Oh, HY, Kim, MK, Lee, M, et al. Macronutrient composition and sodium intake of diet are associated with risk of metabolic syndrome and hypertension in Korean women. PLoS One. 2013. 8:e78088. doi:10.1371/journal.pone.0078088 | Study design
1728 | Oh, SW, Wood, AC, Hwang, SS, et al. Racial and Ethnic Differences in the Association of Low-Carbohydrate Diet With Mortality in the Multi-Ethnic Study of Atherosclerosis. JAMA Netw Open. 2022. 5:e2237552. doi:10.1001/jamanetworkopen.2022.37552 | Intervention/Exposure
1729 | Oh, SY, Ryue, J, Hsieh, CH, et al. Eggs enriched in omega-3 fatty acids and alterations in lipid concentrations in plasma and lipoproteins and in blood pressure. Am J Clin Nutr. Oct 1991;54(4):689-95. doi:10.1093/ajcn/54.4.689 | Intervention/Exposure; Sample size/Power
1730 | Ohman, M, Akerfeldt, T, Nilsson, I, et al. Biochemical effects of consumption of eggs containing omega-3 polyunsaturated fatty acids. Ups J Med Sci. 2008. 113:315-23. doi:10.3109/2000-1967-235 | Intervention/Exposure; Comparator
1731 | Oikonomou, E, Psaltopoulou, T, Georgiopoulos, G, et al. Western Dietary Pattern Is Associated With Severe Coronary Artery Disease. Angiology. 2018. 69:339-346. doi:10.1177/0003319717721603 | Study design; Intervention/Exposure
1732 | Okamoto, T, Kobayashi, R, Natsume, M, et al. Habitual cocoa intake reduces arterial stiffness in postmenopausal women regardless of intake frequency: a randomized parallel-group study. Clinical interventions in aging. 2016. 11:1645-1652. doi:10.2147/CIA.S118152 | Intervention/Exposure; Sample size/Power
1733 | Oken, E, Ning, Y, Rifas-Shiman, SL, et al. Diet during pregnancy and risk of preeclampsia or gestational hypertension. Ann Epidemiol. Sep 2007;17(9):663-8. doi:10.1016/j.annepidem.2007.03.003 | Intervention/Exposure; Outcome
1734 | Okuda, M, Fujiwara, A, Sasaki, S. Adherence to the Japanese Food Guide: The Association between Three Scoring Systems and Cardiometabolic Risks in Japanese Adolescents. Nutrients. 2021. 14:43. doi:10.3390/nu14010043 | Intervention/Exposure
1735 | Okuyama H, Ichikawa Y, Sun Y, Hamazaki T, Lands WE. Mechanisms by which dietary fats affect coronary heart disease mortality. World Rev Nutr Diet. 2007;96:119-141. doi:10.1159/000097811 | Study design; Publication status
1736 | Oldroyd, JC, Unwin, NC, White, M, et al. Randomised controlled trial evaluating the effectiveness of behavioural interventions to modify cardiovascular risk factors in men and women with impaired glucose tolerance: outcomes at 6 months. Diabetes Research and Clinical Practice. Apr 2001;52(1):29-43. doi:Doi 10.1016/S01688227(00)00244-8 | Intervention/Exposure
1737 | Oliveira, A, Rodríguez-Artalejo, F, Gaio, R, et al. Major habitual dietary patterns are associated with acute myocardial infarction and cardiovascular risk markers in a southern European population. J Am Diet Assoc. 2011. 111:241-50. doi:10.1016/j.jada.2010.10.042 | Study design; Intervention/Exposure
1738 | Olmedilla-Alonso B, Granado-Lorencio F, Herrero-Barbudo C, Blanco-Navarro I, Blázquez-García S, Pérez-Sacristán B. Consumption of restructured meat products with added walnuts has a cholesterol-lowering effect in subjects at high cardiovascular risk: a randomised, crossover, placebo-controlled study. J Am Coll Nutr. 2008;27(2):342-348. doi:10.1080/07315724.2008.10719710 | Intervention/Exposure; Sample size/Power
1739 | Olmedilla-Alonso, B, Nova-Rebato, E, García-González, N, et al. Effect of ewe’s (semi-skimmed and whole) and cow’s milk yogurt consumption on the lipid profile of control subjects: a crossover study. Food Nutr Res. 2017. 61:1391669. doi:10.1080/16546628.2017.1391669 | Study design; Comparator
1740 | Olsson E, Larsson SC, Höijer J, Kilander L, Byberg L. Milk and Fermented Milk Consumption and Risk of Stroke: Longitudinal Study. Nutrients. 2022;14(5):1070. doi:10.3390/nu14051070 | Intervention/Exposure; Comparator
1741 | Onning, G, Akesson, B, Oste, R, et al. Effects of consumption of oat milk, soya milk, or cow’s milk on plasma lipids and antioxidative capacity in healthy subjects. Ann Nutr Metab. 1998. 42:211-20. doi:10.1159/000012736 | Intervention/Exposure; Sample size/Power
1742 | Onning, G, Wallmark, A, Persson, M, et al. Consumption of oat milk for 5 weeks lowers serum cholesterol and LDL cholesterol in free-living men with moderate hypercholesterolemia. Ann Nutr Metab. 1999. 43:301-9. doi:10.1159/000012798 | Intervention/Exposure; Comparator
1743 | Oomen, CM, van Erk, MJ, Feskens, EJ, et al. Arginine intake and risk of coronary heart disease mortality in elderly men. Arterioscler Thromb Vasc Biol. Sep 2000;20(9):2134-9. doi:10.1161/01.atv.20.9.2134 | Intervention/Exposure
1744 | Ortega, RM, López-Sobaler, AM, Requejo, AM, et al. The influence of meat consumption on dietary data, iron status and serum lipid parameters in young women. Int J Vitam Nutr Res. 1998;68(4):255-62. | Study design; No confounder adjustment
1745 | Ortega, RM, Quintas, ME, Gaspar, MJ, et al. The influence of saturated fatty acid consumption on energy and nutrient intake, blood lipid levels and iron indicators in a group of young women. Nutrition Research. Apr 1998;18(4):671-682. doi:Doi 10.1016/S0271-5317(98)00053-0 | Intervention/Exposure; Comparator
1746 | Ortega, RM, Requejo, AM, Navia, B, et al. The consumption of milk products in a group of pre-school children: Influence on serum lipid profile. Nutrition Research. Jun 2000;20(6):779-790. doi:Doi 10.1016/S0271-5317(00)00175-5 | Study design
1747 | Osler, M, Andreasen, AH, Heitmann, B, et al. Food intake patterns and risk of coronary heart disease: A prospective cohort study examining the use of traditional scoring techniques. European Journal of Clinical Nutrition. 2002. 56:568-574. doi:10.1038/sj.ejcn.1601360 | Intervention/Exposure
1748 | Osler, M, Heitmann, BL, Gerdes, LU, et al. Dietary patterns and mortality in Danish men and women: a prospective observational study. Br J Nutr. 2001. 85:219-25. doi:10.1079/bjn2000240 | Intervention/Exposure
1749 | O’Sullivan TA, Bremner AP, Mori TA, et al. Regular Fat and Reduced Fat Dairy Products Show Similar Associations with Markers of Adolescent Cardiometabolic Health. Nutrients. 2016;8(1):22. Published 2016 Jan 2. doi:10.3390/nu8010022 | Comparator
1750 | Otsuka R, Tange C, Nishita Y, et al. Fish and Meat Intake, Serum Eicosapentaenoic Acid and Docosahexaenoic Acid Levels, and Mortality in Community-Dwelling Japanese Older Persons. Int J Environ Res Public Health. 2019;16(10):1806. Published 2019 May 21. doi:10.3390/ijerph16101806 | Intervention/Exposure; Outcome
1751 | Otto, CM. Heartbeat: Chocolate and atrial fibrillation. Heart. Aug 2017;103(15):1139-1140. doi:10.1136/heartjnl-2017-312025 | Study design
1752 | Ouellet, V, Weisnagel, SJ, Marois, J, et al. Dietary cod protein reduces plasma C-reactive protein in insulin-resistant men and women. J Nutr. Dec 2008;138(12):2386-91. doi:10.3945/jn.108.092346 | Intervention/Exposure; Sample size/Power
1753 | Ozawa, M, Yoshida, D, Hata, J, et al. Dietary Protein Intake and Stroke Risk in a General Japanese Population: The Hisayama Study. Stroke. Jun 2017;48(6):1478-1486. doi:10.1161/STROKEAHA.116.016059 | Intervention/Exposure
1754 | Pacheco, YM, Bermúdez, B, López, S, et al. Ratio of oleic to palmitic acid is a dietary determinant of thrombogenic and fibrinolytic factors during the postprandial state in men. American Journal of Clinical Nutrition. Aug 2006;84(2):342-349. | Sample size/Power
1755 | Pahkala K, Laitinen TT, Niinikoski H, et al. Effects of 20-year infancy-onset dietary counselling on cardiometabolic risk factors in the Special Turku Coronary Risk Factor Intervention Project (STRIP): 6-year post-intervention follow-up. Lancet Child Adolesc Health. 2020;4(5):359-369. doi:10.1016/S2352-4642(20)30059-6 | Intervention/Exposure
1756 | Pahkala, K, Hietalampi, H, Laitinen, TT, et al Ideal cardiovascular health in adolescence: effect of lifestyle intervention and association with vascular intima-media thickness and elasticity (the Special Turku Coronary Risk Factor Intervention Project for Children [STRIP] study). Circulation. May 28 2013;127(21):2088-96. doi:10.1161/CIRCULATIONAHA.112.000761 | Intervention/Exposure; Population
1757 | Päivärinta, E, Itkonen, ST, Pellinen, T, et al. Replacing Animal-Based Proteins with Plant-Based Proteins Changes the Composition of a Whole Nordic Diet-A Randomised Clinical Trial in Healthy Finnish Adults. Nutrients. Mar 28 2020;12(4)doi:10.3390/nu12040943 | Intervention/Exposure
1758 | Pala, V, Sieri, S, Chiodini, P, et al. Associations of dairy product consumption with mortality in the European Prospective Investigation into Cancer and Nutrition (EPIC)-Italy cohort. Am J Clin Nutr. 2019. 110:1220-1230. doi:10.1093/ajcn/nqz183 | Comparator
1759 | Pala, V, Sieri, S, Masala, G, et al. Associations between dietary pattern and lifestyle, anthropometry and other health indicators in the elderly participants of the EPIC-Italy cohort. Nutr Metab Cardiovasc Dis. 2006. 16:186-201. doi:10.1016/j.numecd.2005.05.009 | Intervention/Exposure
1760 | Palacios, C, Bertrán, JJ, Ríos, RE, et al. No effects of low and high consumption of dairy products and calcium supplements on body composition and serum lipids in Puerto Rican obese adults. Nutrition. 2011. 27:520-5. doi:10.1016/j.nut.2010.02.011 | Sample size/Power
1761 | Palacios, OM, Edirisinghe, I, Wilcox, ML, et al. A Lean Pork-Containing Breakfast Reduces Hunger and Glycemic Response Compared to a Refined Carbohydrate-Containing Breakfast in Adults with Prediabetes. J Am Coll Nutr. 2018. 37:293-301. doi:10.1080/07315724.2017.1396266 | Duration
1762 | Paletas, K, Athanasiadou, E, Sarigianni, M, et al. The protective role of the Mediterranean diet on the prevalence of metabolic syndrome in a population of Greek obese subjects. J Am Coll Nutr. Feb 2010;29(1):41-5. doi:10.1080/07315724.2010.10719815 | Study design
1763 | Pałkowska, E, Bartnikowska, E, Owsiak, D. [The use of low-caloric diet with modified fatty acids pool in the therapy of the metabolic syndrome]. Rocz Panstw Zakl Hig. 2012;63(2):163-9. Wykorzystanie diety ubogoenergetycznej o zmodyfikowanym skladzie puli kwasow tluszczowych w terapii zespolu metabolicznego. | Publication language
1764 | Pan, A, Sun, Q, Bernstein, AM, et al. Red meat consumption and mortality: results from 2 prospective cohort studies. Arch Intern Med. 2012. 172:555-63. doi:10.1001/archinternmed.2011.2287 | Outcome; Comparator
1765 | Pan, F, Wang, Z, Wang, H, et al. Association between Ultra-Processed Food Consumption and Metabolic Syndrome among Adults in China-Results from the China Health and Nutrition Survey. Nutrients. Feb 2023;15(3)doi:ARTN 75210.3390/nu15030752 | Intervention/Exposure
1766 | Pan, L, Chen, L, Lv, J, et al. Association of Red Meat Consumption, Metabolic Markers, and Risk of Cardiovascular Diseases. Front Nutr. 2022. 9:833271. doi:10.3389/fnut.2022.833271 | Country
1767 | Pan, L, Shi, K, Lv, J, et al. Association of dietary patterns, circulating lipid profile, and risk of obesity. Obesity (Silver Spring). 2023. 31:1445-1454. doi:10.1002/oby.23720 | Intervention/Exposure
1768 | Pan, XF, Magliano, DJ, Zheng, M, et al. Seventeen-Year Associations between Diet Quality Defined by the Health Star Rating and Mortality in Australians: The Australian Diabetes, Obesity and Lifestyle Study (AusDiab). Current Developments in Nutrition. Nov 2020;4(11)doi:ARTN nzaa157 10.1093/cdn/nzaa157 | Intervention/Exposure
1769 | Panagiotakos, D, Pitsavos, C, Chrysohoou, C, et al. Dietary patterns and 5-year incidence of cardiovascular disease: a multivariate analysis of the ATTICA study. Nutr Metab Cardiovasc Dis. 2009. 19:253-63. doi:10.1016/j.numecd.2008.06.005 | Intervention/Exposure
1770 | Panagiotakos, DB, Pitsavos, C, Arvaniti, F, et al. Adherence to the Mediterranean food pattern predicts the prevalence of hypertension, hypercholesterolemia, diabetes and obesity, among healthy adults; the accuracy of the MedDietScore. Prev Med. 2007. 44:335-40. doi:10.1016/j.ypmed.2006.12.009 | Study design; Intervention/Exposure
1771 | Panagiotakos, DB, Pitsavos, C, Stefanadis, C. Dietary patterns: a Mediterranean diet score and its relation to clinical and biological markers of cardiovascular disease risk. Nutr Metab Cardiovasc Dis. 2006. 16:559-68. doi:10.1016/j.numecd.2005.08.006 | Intervention/Exposure
1772 | Panagiotakos, DB, Tzima, N, Pitsavos, C, et al. The relationship between dietary habits, blood glucose and insulin levels among people without cardiovascular disease and type 2 diabetes; the ATTICA study. Rev Diabet Stud. 2005. 2:208-15. doi:10.1900/rds.2005.2.208 | Study design; Outcome
1773 | Pang, SJ, Jia, SS, Man, QQ, et al. Dietary Cholesterol in the Elderly Chinese Population: An Analysis of CNHS 2010-2012. Nutrients. Aug 25 2017;9(9)doi:10.3390/nu9090934 | Outcome; Country
1774 | Paniagua, JA, Pérez-Martinez, P, Gjelstad, IM, et al. A low-fat high-carbohydrate diet supplemented with long-chain n-3 PUFA reduces the risk of the metabolic syndrome. Atherosclerosis. 2011. 218:443-450. doi:10.1016/j.atherosclerosis.2011.07.003 | Intervention/Exposure
1775 | Paniagua, JA, Romero, MI, Sanchez, ME, et al. Effect of 3 Model Diets on the Glucose and Insulin Response, Lipid Profile and Endothelial Function in Insulin-Resistant Subjects. Clinica E Investigacion En Arteriosclerosis. Apr 2008;20(2):55-63. doi:Doi 10.1016/S0214-9168(08)72584-1 | Publication language
1776 | Panizza CE, Shvetsov YB, Harmon BE, et al. Testing the Predictive Validity of the Healthy Eating Index-2015 in the Multiethnic Cohort: Is the Score Associated with a Reduced Risk of All-Cause and Cause-Specific Mortality?. Nutrients. 2018;10(4):452. Published 2018 Apr 5. doi:10.3390/nu10040452 | Intervention/Exposure
1777 | Paoli, A, Cenci, L, Grimaldi, KA. Effect of ketogenic Mediterranean diet with phytoextracts and low carbohydrates/high-protein meals on weight, cardiovascular risk factors, body composition and diet compliance in Italian council employees. Nutr J. 2011. 10:112. doi:10.1186/1475-2891-10-112 | Intervention/Exposure
1778 | Papadaki, A, Scott, JA. The Mediterranean eating in Scotland experience project: evaluation of an Internet-based intervention promoting the Mediterranean diet. Br J Nutr. 2005. 94:290-8. doi:10.1079/bjn20051476 | Intervention/Exposure; Sample size/Power
1779 | Papageorgiou, M, Merminod, F, Ferrari, S, et al. Associations of Calcium Intake and Calcium from Various Sources with Blood Lipids in a Population of Older Women and Men with High Calcium Intake. Nutrients. Mar 21 2022;14(6)doi:10.3390/nu14061314 | Study design
1780 | Papanikolaou Y, Fulgoni VL 3rd. Dairy Food Consumption Is Associated with Reduced Risk of Heart Disease Mortality, but Not All-Cause and Cancer Mortality in US Adults. Nutrients. 2023;15(2):394. Published 2023 Jan 12. doi:10.3390/nu15020394 | Intervention/Exposure; Comparator
1781 | Papier, K, Fensom, GK, Knuppel, A, et al. Meat consumption and risk of 25 common conditions: outcome-wide analyses in 475,000 men and women in the UK Biobank study. BMC Med. 2021. 19:53. doi:10.1186/s12916-021-01922-9 | Comparator
1782 | Paradis, G, Fodor, JG. Diet and the prevention of cardiovascular diseases. Can J Cardiol. Dec 1999;15 Suppl G:81G-8G. | Study design; Publication status
1783 | Parfitt, VJ, Desomeaux, K, Bolton, CH, et al Effects of high monounsaturated and polyunsaturated fat diets on plasma lipoproteins and lipid peroxidation in type 2 diabetes mellitus. Diabet Med. Jan-Feb 1994;11(1):85-91. doi:10.1111/j.1464-5491.1994.tb00235.x | Health status; Sample size/Power
1784 | Park, K, Son, J, Jang, J, et al. Unprocessed Meat Consumption and Incident Cardiovascular Diseases in Korean Adults: The Korean Genome and Epidemiology Study (KoGES). Nutrients. May 15 2017;9(5)doi:10.3390/nu9050498 | Intervention/Exposure; Comparator
1785 | Park, S, Ahn, J, Lee, BK. Very-low-fat diets may be associated with increased risk of metabolic syndrome in the adult population. Clin Nutr. 2016. 35:1159-67. doi:10.1016/j.clnu.2015.09.010 | Study design
1786 | Park, S, Kim, K, Lee, BK, et al. A Healthy Diet Rich in Calcium and Vitamin C Is Inversely Associated with Metabolic Syndrome Risk in Korean Adults from the KNHANES 2013-2017. Nutrients. Apr 2021;13(4)doi:ARTN 131210.3390/nu13041312 | Study design
1787 | Park, S, Snook, JT, Bricker, L, et al. Relative effects of high saturated fatty acid levels in meat, dairy products, and tropical oils on serum lipoprotein and low-density lipoprotein degradation by mononuclear cells in healthy males. Metabolism. 1996. 45:550-8. doi:10.1016/s0026-0495(96)90023-2 | Sample size/Power
1788 | Park, SJ, Kim, MS, Choi, SW, et al. The Relationship of Dietary Pattern and Genetic Risk Score with the Incidence Dyslipidemia: 14-Year Follow-Up Cohort Study. Nutrients. Dec 16 2020;12(12)doi:10.3390/nu12123840 | Intervention/Exposure
1789 | Park, SJ, Park, J, Song, HJ, et al. Association between dairy product intake and hypertriglyceridemia in Korean adults. Nutr Res Pract. 2020. 14:152-159. doi:10.4162/nrp.2020.14.2.152 | Study design
1790 | Parr, EB, Coffey, VG, Cato, LE, et al. A randomized trial of high-dairy-protein, variable-carbohydrate diets and exercise on body composition in adults with obesity. Obesity (Silver Spring). May 2016;24(5):1035-45. doi:10.1002/oby.21451 | Sample size/Power
1791 | Parry, SA, Rosqvist, F, Mozes, FE, et al. Intrahepatic Fat and Postprandial Glycemia Increase After Consumption of a Diet Enriched in Saturated Fat Compared With Free Sugars. Diabetes Care. 2020. 43:1134-1141. doi:10.2337/dc19-2331 | Intervention/Exposure; Sample size/Power
1792 | Pasagian-Macaulay, A, Aston, CE, Ferrell, RE, et al. A dietary and behavioral intervention designed to lower coronary heart disease. Risk factors are unaffected by variation at the APOE gene locus. Atherosclerosis. 1997. 132:221-7. doi:10.1016/s0021-9150(97)00091-9 | Intervention/Exposure
1793 | Pastore, RL, Brooks, JT, Carbone, JW. Paleolithic nutrition improves plasma lipid concentrations of hypercholesterolemic adults to a greater extent than traditional heart-healthy dietary recommendations. Nutrition Research. Jun 2015;35(6):474-479. doi:10.1016/j.nutres.2015.05.002 | Sample size/Power
1794 | Patel, L, Alicandro, G, La Vecchia, C. Low-Calorie Beverage Consumption, Diet Quality and Cardiometabolic Risk Factors in British Adults. Nutrients. Sep 7 2018;10(9)doi:10.3390/nu10091261 | Study design; Intervention/Exposure
1795 | Patel, YR, Robbins, JM, Gaziano, JM, et al. Mediterranean, DASH, and Alternate Healthy Eating Index Dietary Patterns and Risk of Death in the Physicians’ Health Study. Article. Nutrients. May 31 2021;13(6)doi:10.3390/nu13061893 | Intervention/Exposure
1796 | Payab, M, Kelishadi, R, Qorbani, M, et al. Association of healthy foods intake with anthropometric measures and blood pressure in a national sample of Iranian children and adolescents: the CASPIAN-IV Study. Minerva Pediatr. Oct 2019;71(5):420-430. doi:10.23736/S0026-4946.16.04337-1 | Study design
1797 | Pedersen, JI, Muller, H, Seljeflot, I, et al. Palm oil versus hydrogenated soybean oil: effects on serum lipids and plasma haemostatic variables. Asia Pac J Clin Nutr. 2005;14(4):348-57. | Duration; Sample size/Power
1798 | Pedersen, MH, Mølgaard, C, Hellgren, LI, et al. Effects of fish oil supplementation on markers of the metabolic syndrome. Journal of Pediatrics. 2010. 157:395-400+400.e1. doi:10.1016/j.jpeds.2010.04.001 | Intervention/Exposure
1799 | Pelkman, CL, Fishell, VK, Maddox, DH, et al. Effects of moderate-fat (from monounsaturated fat) and low-fat weight-loss diets on the serum lipid profile in overweight and obese men and women. Am J Clin Nutr. 2004. 79:204-12. doi:10.1093/ajcn/79.2.204 | Intervention/Exposure
1800 | Pelletier, X, Belbraouet, S, Mirabel, D, et al. A diet moderately enriched in phytosterols lowers plasma cholesterol concentrations in normocholesterolemic humans. Ann Nutr Metab. 1995;39(5):291-5. doi:10.1159/000177875 | Intervention/Exposure; Sample size/Power
1801 | Peña-Orihuela, P, Camargo, A, Rangel-Zuñiga, OA, et al. Antioxidant system response is modified by dietary fat in adipose tissue of metabolic syndrome patients. Journal of Nutritional Biochemistry. 2013. 24:1717-1723. doi:10.1016/j.jnutbio.2013.02.012 | Intervention/Exposure
1802 | Penedo, LA, Nunes, JC, Gama, MA, et al. Intake of butter naturally enriched with cis9,trans11 conjugated linoleic acid reduces systemic inflammatory mediators in healthy young adults. J Nutr Biochem. 2013. 24:2144-51. doi:10.1016/j.jnutbio.2013.08.006 | Intervention/Exposure; Sample size/Power
1803 | Pereira, MA, Jacobs, DR, Jr, Van Horn, et al. Dairy consumption, obesity, and the insulin resistance syndrome in young adults: the CARDIA Study. Jama. 2002. 287:2081-9. doi:10.1001/jama.287.16.2081 | Comparator
1804 | Pereira, T, Bergqvist, J, Vieira, C, et al. Randomized study of the effects of cocoa-rich chocolate on the ventricle-arterial coupling and vascular function of young, healthy adults. Nutrition. 2019. 63-64:175-183. doi:10.1016/j.nut.2019.02.017 | Intervention/Exposure; Comparator; Sample size/Power
1805 | Pereira, T, Maldonado, J, Laranjeiro, M, et al. Central arterial hemodynamic effects of dark chocolate ingestion in young healthy people: a randomized and controlled trial. Cardiol Res Pract. 2014;2014:945951. doi:10.1155/2014/945951 | Comparator
1806 | Pérez Fernández, MR, Martínez Lede, I, Failde Garrido, JM, et al. [Effects of the intake of dairy products naturally enriched with selenium and omega-3 polyunsaturated fatty acids in a sample of postmenopausal women with metabolic syndrome: a randomized, triple-blind, placebo-controlled clinical trial]. Nutr Hosp. Oct 13 2021;38(5):983-992. Efectos de la ingesta de lacteos enriquecidos de forma natural con selenio y omega-3 en una muestra de mujeres posmenopausicas con sindrome metabolico: un ensayo clinico aleatorizado, triple ciego y controlado con placebo. doi:10.20960/nh.03613 | Publication language
1807 | Pérez-Beltrán YE, González-Becerra K, Rivera-Iñiguez I, et al. A Nutrigenetic Strategy for Reducing Blood Lipids and Low-Grade Inflammation in Adults with Obesity and Overweight. Nutrients. 2023;15(20):4324. doi:10.3390/nu15204324 | Intervention/Exposure
1808 | Pérez-Jiménez, F, Castro, P, López-Miranda, J, et al. Circulating levels of endothelial function are modulated by dietary monounsaturated fat. Atherosclerosis. Aug 1999;145(2):351-8. doi:10.1016/s0021-9150(99)00116-1 | Intervention/Exposure; Sample size/Power
1809 | Perez-Jimenez, F, Espino, A, Lopez-Segura, F, et al. Lipoprotein concentrations in normolipidemic males consuming oleic acid-rich diets from two different sources: olive oil and oleic acid-rich sunflower oil. Am J Clin Nutr. Oct 1995;62(4):769-75. doi:10.1093/ajcn/62.4.769 | Intervention/Exposure
1810 | Pérez-Jiménez, F, López-Miranda, J, Pinillos, MD, et al. A Mediterranean and a high-carbohydrate diet improve glucose metabolism in healthy young persons. Diabetologia. 2001. 44:2038-2043. doi:10.1007/s001250100009 | Intervention/Exposure
1811 | Perez-Martinez P, Perez-Jimenez F, Ordovas JM, et al. The APOB −516C/T polymorphism has no effect on lipid and apolipoprotein response following changes in dietary fat intake in a healthy population. Nutr Metab Cardiovasc Dis. 2007;17(3):224-229. doi:10.1016/j.numecd.2005.11.010 | Intervention/Exposure
1812 | Perez-Martinez, P, Lopez-Miranda, J, Blanco-Colio, L, et al. The chronic intake of a Mediterranean diet enriched in virgin olive oil, decreases nuclear transcription factor κB activation in peripheral blood mononuclear cells from healthy men. Atherosclerosis. 2007. 194:e141-e146. doi:10.1016/j.atherosclerosis.2006.11.033 | Intervention/Exposure; Sample size/Power
1813 | Perez-Martinez, P, Ordovas, JM, Garcia-Rios, A, et al. Consumption of diets with different type of fat influences triacylglycerols-rich lipoproteins particle number and size during the postprandial state. Nutrition, metabolism, and cardiovascular diseases : NMCD. 2011. 21:39-45. doi:10.1016/j.numecd.2009.07.008 | Duration; Sample size/Power
1814 | Perichart-Perera, O, Balas-Nakash, M, Rodríguez-Cano, A, et al. Correlates of dietary energy sources with cardiovascular disease risk markers in Mexican school-age children. J Am Diet Assoc. Feb 2010;110(2):253-60. doi:10.1016/j.jada.2009.10.031 | Study design
1815 | Perona, JS, Cañizares, J, Montero, E, et al. Virgin olive oil reduces blood pressure in hypertensive elderly subjects. Clin Nutr. Oct 2004;23(5):1113-21. doi:10.1016/j.clnu.2004.02.004 | Intervention/Exposure
1816 | Perona, JS, Covas, MI, Fitó, M, et al. Reduction in systemic and VLDL triacylglycerol concentration after a 3-month Mediterranean-style diet in high-cardiovascular-risk subjects. Journal of nutritional biochemistry. 2010. 21:892-898. doi:10.1016/j.jnutbio.2009.07.005 | Intervention/Exposure
1817 | Perry, CA, Van Guilder, GP, Hossain, M, et al. Cardiometabolic Changes in Response to a Calorie-Restricted DASH Diet in Obese Older Adults. Front Nutr. 2021. 8:647847. doi:10.3389/fnut.2021.647847 | Intervention/Exposure; Comparator
1818 | Petermann-Rocha F, Celis-Morales C, Pell JP, Ho FK. Do all vegetarians have a lower cardiovascular risk? A prospective study. Clin Nutr. 2023;42(3):269-276. doi:10.1016/j.clnu.2023.01.010 | Intervention/Exposure
1819 | Petermann-Rocha, F, Ho, FK, Foster, H, et al. Nonlinear - Associations Between Cumulative Dietary Risk Factors and Cardiovascular Diseases, Cancer, and All-Cause Mortality: A Prospective Cohort Study From UK Biobank. Mayo Clinic Proceedings. Sep 2021;96(9):2418-2431. doi:10.1016/j.mayocp.2021.01.036 | Intervention/Exposure
1820 | Petermann-Rocha, F, Parra-Soto, S, Gray, S, et al. Vegetarians, fish, poultry, and meat-eaters: who has higher risk of cardiovascular disease incidence and mortality? A prospective study from UK Biobank. Eur Heart J. 2021. 42:1136-1143. doi:10.1093/eurheartj/ehaa939 | Comparator
1821 | Petersen K, Murphy J, Whitbread J, Clifton P, Keogh J. The Effects of a Hypocaloric Diet Containing Peanuts on Weight Loss, Glycemic Control and Blood Pressure: A 6-Month Randomized Controlled Trial. Curr Dev Nutr. 2022;6(Suppl 1):1083. doi:10.1093/cdn/nzac070.042 | Intervention/Exposure; Publication status
1822 | Petersen, KS, Keogh, JB, Lister, N, et al. Association between dairy intake, lipids and vascular structure and function in diabetes. World Journal of Diabetes. May 15 2017;8(5):202-212. doi:10.4239/wjd.v8.i5.202 | Health status
1823 | Petersen, KS, Murphy, J, Whitbread, J, et al. The Effect of a Peanut-Enriched Weight Loss Diet Compared to a Low-Fat Weight Loss Diet on Body Weight, Blood Pressure, and Glycemic Control: A Randomized Controlled Trial. Nutrients. Jul 21 2022;14(14)doi:10.3390/nu14142986 | Intervention/Exposure
1824 | Petersen, M, Taylor, MA, Saris, WH, et al. Randomized, multi-center trial of two hypo-energetic diets in obese subjects: high- versus low-fat content. Int J Obes (Lond). Mar 2006;30(3):552-60. doi:10.1038/sj.ijo.0803186 | Intervention/Exposure
1825 | Petrogianni, M, Grammatikaki, E, Kalogeropoulos, N, et al. Additional benefit in CVD risk indices derived from the consumption of fortified milk when combined with a lifestyle intervention. Public Health Nutr. 2014. 17:440-9. doi:10.1017/s1368980012005265 | Intervention/Exposure; Comparator
1826 | Petrogianni, M, Grammatikaki, E, Pitsavos, C, et al. Changes in CVD risk factors after combined dietary counselling and supplementation with lipid-lowering milk product: the effect of compliance. e-SPEN Journal. 2012;7(5):e205-e210. doi:10.1016/j.clnme.2012.06.002 | Intervention/Exposure; Comparator
1827 | Petrogianni, M, Kanellakis, S, Kallianioti, K, et al. multicomponent lifestyle intervention produces favourable changes in diet quality and cardiometabolic risk indices in hypercholesterolaemic adults. J Hum Nutr Diet. Dec 2013;26(6):596-605. doi:10.1111/jhn.12041 | Intervention/Exposure; Comparator
1828 | Petrogianni, M, Kanellakis, S, Moschonis, G, et al. Fortification of vitamin A in a phytosterol enriched milk maintains plasma beta-carotene levels. J Food Sci Technol. 2014. 51:196-9. doi:10.1007/s13197-013-1103-y | Outcome; Comparator
1829 | Petrone AB, Gaziano JM, Djoussé L. Chocolate consumption and risk of heart failure in the Physicians’ Health Study. Eur J Heart Fail. 2014;16(12):1372-1376. doi:10.1002/ejhf.180 | Comparator
1830 | Pettersen BJ, Anousheh R, Fan J, Jaceldo-Siegl K, Fraser GE. Vegetarian diets and blood pressure among white subjects: results from the Adventist Health Study-2 (AHS2). Public Health Nutr. 2012;15(10):1909-1916. doi:10.1017/S1368980011003454 | Intervention/Exposure
1831 | Pettman TL, Buckley JD, Misan GM, Coates AM, Howe PR. Health benefits of a 4-month group-based diet and lifestyle modification program for individuals with metabolic syndrome. Obes Res Clin Pract. 2009;3(4):221-235. doi:10.1016/j.orcp.2009.06.002 | Intervention/Exposure
1832 | Petyaev, IM, Bashmakov, YK. Could cheese be the missing piece in the French paradox puzzle?. Med Hypotheses. 2012. 79:746-9. doi:10.1016/j.mehy.2012.08.018 | Study design
1833 | Petyaev, IM, Dovgalevsky, PY, Chalyk, NE, et al. Reduction in blood pressure and serum lipids by lycosome formulation of dark chocolate and lycopene in prehypertension. Food Sci Nutr. 2014. 2:744-50. doi:10.1002/fsn3.169 | Comparator; Sample size/Power
1834 | Petzke, KJ, Lemke, S, Klaus, S. Increased fat-free body mass and no adverse effects on blood lipid concentrations 4 weeks after additional meat consumption in comparison with an exclusion of meat in the diet of young healthy women. J Nutr Metab. 2011. 2011:210930. doi:10.1155/2011/210930 | Sample size/Power
1835 | Philis-Tsimikas A, Fortmann AL, Dharkar-Surber S, et al. Dulce Mothers: an intervention to reduce diabetes and cardiovascular risk in Latinas after gestational diabetes. Transl Behav Med. 2014;4(1):18-25. doi:10.1007/s13142-014-0253-4 | Study design; Intervention/Exposure
1836 | Phillips CM, Goumidi L, Bertrais S, et al. Dietary saturated fat, gender and genetic variation at the TCF7L2 locus predict the development of metabolic syndrome. J Nutr Biochem. 2012;23(3):239-244. doi:10.1016/j.jnutbio.2010.11.020 | Intervention/Exposure; Outcome
1837 | Phillips CM, Kesse-Guyot E, Ahluwalia N, et al. Dietary fat, abdominal obesity and smoking modulate the relationship between plasma complement component 3 concentrations and metabolic syndrome risk. Atherosclerosis. 2012;220(2):513-519. doi:10.1016/j.atherosclerosis.2011.11.007 | Intervention/Exposure
1838 | Piccolo BD, Keim NL, Fiehn O, Adams SH, Van Loan MD, Newman JW. Habitual physical activity and plasma metabolomic patterns distinguish individuals with low vs. high weight loss during controlled energy restriction. J Nutr. 2015;145(4):681-690. doi:10.3945/jn.114.201574 | Intervention/Exposure
1839 | Pickering, RT, Bradlee, ML, Singer, MR, et al. Baseline diet modifies the effects of dietary change. Br J Nutr. 2020. 123:951-958. doi:10.1017/s0007114520000112 | Comparator
1840 | Piers LS, Walker KZ, Stoney RM, Soares MJ, O’Dea K. Substitution of saturated with monounsaturated fat in a 4-week diet affects body weight and composition of overweight and obese men. Br J Nutr. 2003;90(3):717-727. doi:10.1079/bjn2003948 | Intervention/Exposure
1841 | Pierucci, P, Misciagna, G, Ventura, MT, et al. Diet and myocardial infarction: a nested case-control study in a cohort of elderly subjects in a Mediterranean area of southern Italy. Nutr Metab Cardiovasc Dis. 2012. 22:727-33. doi:10.1016/j.numecd.2010.12.002 | Intervention/Exposure
1842 | Pięta A, Frączek B, Wiecek M, Mazur-Kurach P. Impact of Paleo Diet on Body Composition, Carbohydrate and Fat Metabolism of Professional Handball Players. Nutrients. 2023;15(19):4155. Published 2023 Sep 26. doi:10.3390/nu15194155 | Intervention/Exposure; Sample size/Power
1843 | Pieters, DJ, Zock, PL, Fuchs, D, et al. Effect of α-linolenic acid on 24-h ambulatory blood pressure in untreated high-normal and stage I hypertensive subjects. Br J Nutr. 2019. 121:155-163. doi:10.1017/s0007114518003094 | Intervention/Exposure
1844 | Pieters, DJM, Mensink, RP. Effects of stearidonic acid on serum triacylglycerol concentrations in overweight and obese subjects: A randomized controlled trial. European Journal of Clinical Nutrition. 2015. 69:121-126. doi:10.1038/ejcn.2014.193 | Intervention/Exposure
1845 | Pieterse Z, Jerling JC, Oosthuizen W, et al. Substitution of high monounsaturated fatty acid avocado for mixed dietary fats during an energy-restricted diet: effects on weight loss, serum lipids, fibrinogen, and vascular function. Nutrition. 2005;21(1):67-75. doi:10.1016/j.nut.2004.09.010 | Intervention/Exposure; Sample size/Power
1846 | Pietinen P, Lahti-Koski M, Vartiainen E, Puska P. Nutrition and cardiovascular disease in Finland since the early 1970s: a success story. J Nutr Health Aging. 2001;5(3):150-154. | Study design
1847 | Pietinen P, Vartiainen E, Seppänen R, Aro A, Puska P. Changes in diet in Finland from 1972 to 1992: impact on coronary heart disease risk. Prev Med. 1996;25(3):243-250. doi:10.1006/pmed.1996.0053 | Study design
1848 | Pietinen, P, Ascherio, A, Korhonen, P, et al. Intake of fatty acids and risk of coronary heart disease in a cohort of Finnish men. The Alpha-Tocopherol, Beta-Carotene Cancer Prevention Study. Am J Epidemiol. 1997. 145:876-87. doi:10.1093/oxfordjournals.aje.a009047 | Intervention/Exposure
1849 | Pigsborg, K, Gürdeniz, G, Rangel-Huerta, OD, et al. Effects of changing from a diet with saturated fat to a diet with n-6 polyunsaturated fat on the serum metabolome in relation to cardiovascular disease risk factors. Eur J Nutr. 2022. 61:2079-2089. doi:10.1007/s00394-021-02796-6 | Intervention/Exposure
1850 | Pine DA, Madlon-Kay DJ, Sauser M. Effectiveness of a nurse-based intervention in a community practice on patients’ dietary fat intake and total serum cholesterol level. Arch Fam Med. 1997;6(2):129-134. doi:10.1001/archfami.6.2.129 | Study design; Intervention/Exposure
1851 | Pinto, A, Santos, AC, Lopes, C, et al. Dietary patterns at 7 year-old and their association with cardiometabolic health at 10 year-old. Clin Nutr. 2020. 39:1195-1202. doi:10.1016/j.clnu.2019.05.007 | Intervention/Exposure
1852 | Pintus, S, Murru, E, Carta, G, et al. Sheep cheese naturally enriched in α-linolenic, conjugated linoleic and vaccenic acids improves the lipid profile and reduces anandamide in the plasma of hypercholesterolaemic subjects. British journal of nutrition. 2013. 109:1453-1462. doi:10.1017/S0007114512003224 | Duration
1853 | Plaisted, CS, Lin, PH, Ard, JD, et al. The effects of dietary patterns on quality of life: a substudy of the Dietary Approaches to Stop Hypertension trial. J Am Diet Assoc. 1999. 99:S84-9. doi:10.1016/s0002-8223(99)00421-6 | Intervention/Exposure; Outcome
1854 | Plat, J, van Onselen, EN, van Heugten, MM, et al. Effects on serum lipids, lipoproteins and fat soluble antioxidant concentrations of consumption frequency of margarines and shortenings enriched with plant stanol esters. Eur J Clin Nutr. 2000. 54:671-7. doi:10.1038/sj.ejcn.1601071 | Intervention/Exposure
1855 | Pokala A, Quarles WR, Ortega-Anaya J, et al. Milk-Fat-Globule-Membrane-Enriched Dairy Milk Compared with a Soy-Lecithin-Enriched Beverage Did Not Adversely Affect Endotoxemia or Biomarkers of Gut Barrier Function and Cardiometabolic Risk in Adults with Metabolic Syndrome: A Randomized Controlled Crossover Trial. Nutrients. 2023.15(14):3259. doi:10.3390/nu15143259 | Duration
1856 | Polychronopoulos, E, Pounis, G, Bountziouka, V, et al. Dietary meat fats and burden of cardiovascular disease risk factors, in the elderly: a report from the MEDIS study. Lipids Health Dis. 2010. 9:30. doi:10.1186/1476-511x-9-30 | Study design
1857 | Ponzo V, Gentile L, Gambino R, et al. Incidence of diabetes mellitus, cardiovascular outcomes and mortality after a 12-month lifestyle intervention: A 9-year follow-up. Diabetes Metab. 2018;44(5):449-451. doi:10.1016/j.diabet.2018.04.008 | Intervention/Exposure
1858 | Poppitt SD, Keogh GF, Prentice AM, et al. Long-term effects of ad libitum low-fat, high-carbohydrate diets on body weight and serum lipids in overweight subjects with metabolic syndrome. Am J Clin Nutr. 2002;75(1):11-20. doi:10.1093/ajcn/75.1.11 | Intervention/Exposure
1859 | Porter Starr, KN, Connelly, MA, Orenduff, MC, et al. Impact on cardiometabolic risk of a weight loss intervention with higher protein from lean red meat: Combined results of 2 randomized controlled trials in obese middle-aged and older adults. J Clin Lipidol. 2019. 13:920-931. doi:10.1016/j.jacl.2019.09.012 | Intervention/Exposure; Comparator
1860 | Posner, BM, Cupples, LA, Franz, MM, et al. Diet and heart disease risk factors in adult American men and women: the Framingham Offspring-Spouse nutrition studies. International Journal of Epidemiology. 1993. 22:1014-1025. doi: 10.1093/ije/22.6.1014 | Study design; Intervention/Exposure
1861 | Post, GB, Kemper, HC, Twisk, J, et al. The association between dietary patterns and cardio vascular disease risk indicators in healthy youngsters: results covering fifteen years of longitudinal development. Eur J Clin Nutr. 1997. 51:387-93. doi:10.1038/sj.ejcn.1600419 | Intervention/Exposure
1862 | Pouliot-Mathieu, K, Gardner-Fortier, C, Lemieux, S, et al. Effect of cheese containing gamma-aminobutyric acid-producing lactic acid bacteria on blood pressure in men. PharmaNutrition. 2013. 1:141-18. doi:10.1016/j.phanu.2013.06.003 | Comparator
1863 | Praagman J, Vissers LET, Mulligan AA, et al. Consumption of individual saturated fatty acids and the risk of myocardial infarction in a UK and a Danish cohort. Int J Cardiol. 2019;279:18-26. doi:10.1016/j.ijcard.2018.10.064 | Intervention/Exposure
1864 | Praagman, J, Beulens, JW, Alssema, M, et al. The association between dietary saturated fatty acids and ischemic heart disease depends on the type and source of fatty acid in the European Prospective Investigation into Cancer and Nutrition-Netherlands cohort. Am J Clin Nutr. 2016. 103:356-65. doi:10.3945/ajcn.115.122671 | Intervention/Exposure; Comparator
1865 | Praagman, J, Dalmeijer, GW, van der Schouw, YT, et al. The relationship between fermented food intake and mortality risk in the European Prospective Investigation into Cancer and Nutrition-Netherlands cohort. Br J Nutr. 2015. 113:498-506. doi:10.1017/s0007114514003766 | Intervention/Exposure; Comparator
1866 | Praagman, J, de Jonge, EA, Kiefte-de Jong, JC, et al. Dietary Saturated Fatty Acids and Coronary Heart Disease Risk in a Dutch Middle-Aged and Elderly Population. Arterioscler Thromb Vasc Biol. Sep 2016;36(9):2011-8. doi:10.1161/ATVBAHA.116.307578 | Intervention/Exposure; Comparator
1867 | Praagman, J, Franco, OH, Ikram, MA, et al. Dairy products and the risk of stroke and coronary heart disease: the Rotterdam Study. Eur J Nutr. Sep 2015;54(6):981-90. doi:10.1007/s00394-014-0774-0 | Comparator
1868 | Prater, MC, Scheurell, AR, Paton, CM, et al. Blood Lipid Responses to Diets Enriched with Cottonseed Oil Compared with Olive Oil in Adults with High Cholesterol in a Randomized Trial. Journal of Nutrition. 2022. 152:2060-2071. doi:10.1093/jn/nxac099 | Intervention/Exposure
1869 | Prater, MC, Scheurell, AR, Paton, CM, et al. Comparison of Blood Lipid Responses to Diets Enriched with Cottonseed Oil vs. Olive Oil in Adults with High Cholesterol in a Randomized Trial. Journal of Nutrition. 2022. doi: 10.1093/jn/nxac099 | Intervention/Exposure
1870 | Preis SR, Stampfer MJ, Spiegelman D, Willett WC, Rimm EB. Lack of association between dietary protein intake and risk of stroke among middle-aged men. Am J Clin Nutr. 2010;91(1):39-45. doi:10.3945/ajcn.2009.28060 | Intervention/Exposure
1871 | Preis, SR, Stampfer, MJ, Spiegelman, D, et al. Dietary protein and risk of ischemic heart disease in middle-aged men. Am J Clin Nutr. 2010. 92:1265-72. doi:10.3945/ajcn.2010.29626 | Intervention/Exposure
1872 | Prentice RL, Vasan S, Tinker LF, et al. Metabolomics-Based Biomarker for Dietary Fat and Associations with Chronic Disease Risk in Postmenopausal Women. J Nutr. 2023;153(9):2651-2662. doi:10.1016/j.tjnut.2023.05.021 | Intervention/Exposure
1873 | Prentice, RL, Aragaki, AK, Howard, BV, et al. Low-fat dietary pattern among postmenopausal women influences long-Term cancer, cardiovascular disease, and diabetes outcomes. Journal of Nutrition. 2019. 149:1565-1574. doi:10.1093/jn/nxz107 | Intervention/Exposure
1874 | Prentice, RL, Aragaki, AK, Van Horn, L, et al. Low-fat dietary pattern and cardiovascular disease: results from the Women’s Health Initiative randomized controlled trial. American journal of clinical nutrition. 2017. 106:35-43. doi:10.3945/ajcn.117.153270 | Intervention/Exposure
1875 | Prentice, RL, Aragaki, AK, Van Horn, L, et al. Mortality Associated with Healthy Eating Index Components and an Empirical-Scores Healthy Eating Index in a Cohort of Postmenopausal Women. J Nutr. 2022. 152:2493-2504. doi:10.1093/jn/nxac068 | Comparator
1876 | Prewitt TE, Unterman TG, Glick R, et al. Insulin-like growth factor I and low-density-lipoprotein cholesterol in women during high- and low-fat feeding. Am J Clin Nutr. 1992;55(2):381-384. doi:10.1093/ajcn/55.2.381 | Intervention/Exposure; Sample size/Power
1877 | Prinelli, F, Yannakoulia, M, Anastasiou, CA, et al. Mediterranean diet and other lifestyle factors in relation to 20-year all-cause mortality: A cohort study in an Italian population. British Journal of Nutrition. 2015. 113:1003-1011. doi:10.1017/S0007114515000318 | Outcome
1878 | Probstfield, JL, Rifkind, BM. The Lipid Research Clinics Coronary Primary Prevention Trial: design, results, and implications. Eur J Clin Pharmacol. 1991. 40 Suppl 1:S69-75. doi:10.1007/bf03216294 | Study design; Intervention/Exposure
1879 | Prodhan UK, Milan AM, Thorstensen EB, et al. Altered Dairy Protein Intake Does Not Alter Circulatory Branched Chain Amino Acids in Healthy Adults: A Randomized Controlled Trial. Nutrients. 2018;10(10):1510. doi:10.3390/nu10101510 | Outcome
1880 | Properzi C, O’Sullivan TA, Sherriff JL, et al. Ad Libitum Mediterranean and Low-Fat Diets Both Significantly Reduce Hepatic Steatosis: A Randomized Controlled Trial. Hepatology. 2018;68(5):1741-1754. doi:10.1002/hep.30076 | Health status
1881 | Psaltopoulou, T, Naska, A, Orfanos, P, et al. Olive oil, the Mediterranean diet, and arterial blood pressure: the Greek European Prospective Investigation into Cancer and Nutrition (EPIC) study. Am J Clin Nutr. 2004. 80:1012-8. doi:10.1093/ajcn/80.4.1012 | Study design
1882 | Psota TL, Tindall AM, Lohse B, Miller PE, Petersen KS, Kris-Etherton PM. The Weight Optimization Revamping Lifestyle using the Dietary Guidelines (WORLD) Study: Sustained Weight Loss Over 12 Months. Obesity (Silver Spring). 2020;28(7):1235-1244. doi:10.1002/oby.22824 | Intervention/Exposure
1883 | Puaschitz, NG, Strand, E, Norekvål, TM, et al. Dietary intake of saturated fat is not associated with risk of coronary events or mortality in patients with established coronary artery disease. J Nutr. 2015. 145:299-305. doi:10.3945/jn.114.203505 | Intervention/Exposure; Health status
1884 | Puiggrós, C, Chacón, P, Armadans, LI, et al. Effects of oleic-rich and omega-3-rich diets on serum lipid pattern and lipid oxidation in mildly hypercholesterolemic patients. Clinical Nutrition. 2002. 21:79-87. doi:10.1054/clnu.2001.0511 | Intervention/Exposure; Comparator; Sample size/Power
1885 | Puska, P, Korpelainen, V, Høie, LH, et al. Isolated soya protein with standardised levels of isoflavones, cotyledon soya fibres and soya phospholipids improves plasma lipids in hypercholesterolaemia: a double-blind, placebo-controlled trial of a yoghurt formulation. Br J Nutr. 2004. 91:393-401. doi:10.1079/bjn20031074 | Intervention/Exposure; Comparator
1886 | Qi Q, Durst R, Schwarzfuchs D, et al. CETP genotype and changes in lipid levels in response to weight-loss diet intervention in the POUNDS LOST and DIRECT randomized trials. J Lipid Res. 2015;56(3):713-721. doi:10.1194/jlr.P055715 | Intervention/Exposure
1887 | Qin, C, Lv, J, Yu, C, et al. Dietary patterns and cardiometabolic diseases in 0.5 million Chinese adults: a 10-year cohort study. Nutr J. 2021. 20:74. doi:10.1186/s12937-021-00730-4 | Intervention/Exposure; Country
1888 | Qiu, D, Mei, J, Tanihata, T, et al. A cohort study on cerebrovascular disease in middle-aged and elderly population in rural areas in Jiangxi Province, China. J Epidemiol. 2003. 13:149-56. doi:10.2188/jea.13.149 | Country
1889 | Quek, RYC, Peh, EWY, Henry, CJ. Effects of Cocoa Butter and Cocoa Butter Equivalent in a Chocolate Confectionery on Human Blood Triglycerides, Glucose and Insulin. Foods. 2020. 9:455. doi:10.3390/foods9040455 | Duration
1890 | Quintana Pacheco, DA, Sookthai, D, Wittenbecher, C, et al. Red meat consumption and risk of cardiovascular diseases-is increased iron load a possible link?. Am J Clin Nutr. 2018. 107:113-119. doi:10.1093/ajcn/nqx014 | Comparator
1891 | Quivers ES, Driscoll DJ, Garvey CD, et al. The effects of diet on serum cholesterol in children. Ann N Y Acad Sci. 1991;623:133-134. doi:10.1111/j.1749-6632.1991.tb43724.x | Study design; Intervention/Exposure
1892 | Qureshi AA, Qureshi N, Wright JJ, et al. Lowering of serum cholesterol in hypercholesterolemic humans by tocotrienols (palmvitee). Am J Clin Nutr. 1991;53(4 Suppl):1021S-1026S. doi:10.1093/ajcn/53.4.1021S | Intervention/Exposure; Sample size/Power
1893 | Raben A, Jensen ND, Marckmann P, Sandström B, Astrup A. Spontaneous weight loss during 11 weeks’ ad libitum intake of a low fat/high fiber diet in young, normal weight subjects. 1995;19(12):916-23. | Intervention/Exposure; Sample size/Power
1894 | Radtke T, Schmid A, Trepp A, et al. Short-term effects of trans fatty acids from ruminant and industrial sources on surrogate markers of cardiovascular risk in healthy men and women: A randomized, controlled, double-blind trial. 2017;24(5):534-543. doi:10.1177/2047487316680691 | Intervention/Exposure
1895 | Rafey MF, Abdalgwad R, O’Shea PM, et al. Changes in the leptin to adiponectin ratio are proportional to weight loss after meal replacement in adults with severe obesity. Front Nutr. 2022;9:845574. doi:10.3389/fnut.2022.845574 | Intervention/Exposure; Outcome
1896 | Raff M, Tholstrup T, Basu S, Nonboe P, Sorensen MT, Straarup EM. A diet rich in conjugated linoleic acid and butter increases lipid peroxidation but does not affect atherosclerotic, inflammatory, or diabetic risk markers in healthy young men. J Nutr. 2008;138(3):509-14. doi:10.1093/jn/138.3.509 | Sample size/Power
1897 | Raisi-Estabragh Z, McCracken C, Gkontra P, et al. Associations of meat and fish consumption with conventional and radiomics cardiovascular magnetic resonance phenotypes in the UK biobank. Front Cardiovasc Med. 2021;8:667849. doi:10.3389/fcvm.2021.667849 | Outcome
1898 | Raitakari OT, Porkka KV, Rasanen L, Ronnemaa T, Viikari JS. Clustering and six year cluster-tracking of serum total cholesterol, HDL-cholesterol and diastolic blood pressure in children and young adults. The Cardiovascular Risk in Young Finns Study. J Clin Epidemiol. 1994;47(10):1085-93. doi:10.1016/0895-4356(94)90094-9 | Intervention/Exposure
1899 | Raitakari OT, Porkka KV, Rasanen L, Viikari JS. Relations of life-style with lipids, blood pressure and insulin in adolescents and young adults. The Cardiovascular Risk in Young Finns Study. Atherosclerosis. 1994;111(2):237-46. doi:10.1016/00219150(94)90098-1 | Intervention/Exposure
1900 | Rajaie S, Azadbakht L, Khazaei M, Sherbafchi M, Esmaillzadeh A. Moderate replacement of carbohydrates by dietary fats affects features of metabolic syndrome: a randomized crossover clinical trial. Nutrition. 2014;30(1):61-8. doi:10.1016/j.nut.2013.06.011 | Intervention/Exposure
1901 | Rajaie S, Azadbakht L, Saneei P, Khazaei M, Esmaillzadeh A. Comparative effects of carbohydrate versus fat restriction on serum levels of adipocytokines, markers of inflammation, and endothelial function among women with the metabolic syndrome: A randomized cross-over clinical trial. Ann Nutr Metab. 2013;63(1-2):159-167. doi:10.1159/000354868 | Intervention/Exposure
1902 | Rajaram S, Connell KM, Sabate J. Effect of almond-enriched high-monounsaturated fat diet on selected markers of inflammation: a randomised, controlled, crossover study. Br J Nutr. 2010;103(6):907-12. doi:10.1017/S0007114509992480 | Intervention/Exposure
1903 | Rallidis LS, Lekakis J, Kolomvotsou A, et al. Close adherence to a Mediterranean diet improves endothelial function in subjects with abdominal obesity. Am J Clin Nutr. 2009;90(2):263-8. doi:10.3945/ajcn.2008.27290 | Intervention/Exposure
1904 | Ramel A, Martinez JA, Kiely M, Bandarra NM, Thorsdottir I. Moderate consumption of fatty fish reduces diastolic blood pressure in overweight and obese European young adults during energy restriction. Nutrition. 2010;26(2):168-74. doi:10.1016/j.nut.2009.04.002 | Intervention/Exposure
1905 | Ramprasath VR, Jones PJ, Buckley DD, Woollett LA, Heubi JE. Decreased plasma cholesterol concentrations after PUFA-rich diets are not due to reduced cholesterol absorption/synthesis. Lipids. 2012;47(11):1063-71. doi:10.1007/s11745-012-3708-8 | Intervention/Exposure; Sample size/Power
1906 | Ramsden CE, Hibbeln JR, Majchrzak-Hong SF. All PUFAs are not created equal: absence of CHD benefit specific to linoleic acid in randomized controlled trials and prospective observational cohorts. World Rev Nutr Diet. 2011;102:30-43. doi:10.1159/000327789 | Study design
1907 | Ramsden CE, Zamora D, Majchrzak-Hong S, et al. Re-evaluation of the traditional diet-heart hypothesis: analysis of recovered data from Minnesota Coronary Experiment (1968-73). BMJ. 2016;353:i1246. doi:10.1136/bmj.i1246 | Intervention/Exposure
1908 | Ranabhat CL, Park MB, Kim CB. Influence of alcohol and red meat consumption on life expectancy: Results of 164 Countries from 1992 to 2013. Nutrients. 2020;12(2):459. doi:10.3390/nu12020459 | Study design
1909 | Rancourt-Bouchard M, Gigleux I, Guay V, et al. Effects of regular-fat and low-fat dairy consumption on daytime ambulatory blood pressure and other cardiometabolic risk factors: a randomized controlled feeding trial. Am J Clin Nutr. 2020;111(1):42-51. doi:10.1093/ajcn/nqz251 | Intervention/Exposure; Comparator
1910 | Rangan AM, Flood VL, Denyer G, et al. The effect of dairy consumption on blood pressure in mid-childhood: CAPS cohort study. Eur J Clin Nutr. 2012;66(6):652-7. doi:10.1038/ejcn.2011.218 | Intervention/Exposure; Comparator
1911 | Rangel-Zúñiga OA, Camargo A, Marin C, et al. Proteome from patients with metabolic syndrome is regulated by quantity and quality of dietary lipids. BMC genomics. 2015;16(1):509. doi:10.1186/s12864-015-1725-8 | Intervention/Exposure; Sample size/Power
1912 | Rantala M, Savolainen MJ, Kervinen K, Kesaniemi YA. Apolipoprotein E phenotype and diet-induced alteration in blood pressure. Am J Clin Nutr. 1997;65(2):543-50. doi:10.1093/ajcn/65.2.543 | Intervention/Exposure; Sample size/Power
1913 | Ras RT, Fuchs D, Koppenol WP, et al. The effect of a low-fat spread with added plant sterols on vascular function markers: results of the Investigating Vascular Function Effects of Plant Sterols (INVEST) study. Am J Clin Nutr. Apr 2015;101(4):733-41. doi:10.3945/ajcn.114.102053 | Comparator
1914 | Räsänen M, Lehtinen JC, Niinikoski H, et al. Dietary patterns and nutrient intakes of 7-year-old children taking part in an atherosclerosis prevention project in Finland. J Am Diet Assoc. 2002;102(4):518-24. doi:10.1016/s0002-8223(02)90118-5 | Study design; Outcome
1915 | Rasmussen BM, Vessby B, Uusitupa M, et al. Effects of dietary saturated, monounsaturated, and n-3 fatty acids on blood pressure in healthy subjects. Am J Clin Nutr. 2006;83(2):221-6. doi:10.1093/ajcn/83.2.221 | Intervention/Exposure
1916 | Ravnskov U. Cholesterol was healthy in the end. World Rev Nutr Diet. 2009;100:90-109. doi:10.1159/000235715 | Study design
1917 | Raziani F, Ebrahimi P, Engelsen SB, Astrup A, Raben A, Tholstrup T. Consumption of regular-fat vs reduced-fat cheese reveals gender-specific changes in LDL particle size - a randomized controlled trial. Nutr Metab (Lond). 2018;15:61. doi:10.1186/s12986-0180300-0 | Sample size/Power
1918 | Razmpoosh E, Zare S, Fallahzadeh H, Safi S, Nadjarzadeh A. Effect of a low energy diet, containing a high protein, probiotic condensed yogurt, on biochemical and anthropometric measurements among women with overweight/obesity: A randomised controlled trial. Clin Nutr ESPEN. 2020;35:194-200. doi:10.1016/j.clnesp.2019.10.001 | Comparator
1919 | Razquin C, Ruiz-Canela M, Wernitz A, et al. Effects of supplemented mediterranean diets on plasma-phospholipid fatty acid profiles and risk of cardiovascular disease after 1 year of intervention in the PREDIMED trial. Clin Chem. 2023;69(3):283-294. doi:10.1093/clinchem/hvac221 | Intervention/Exposure
1920 | Reaven P, Parthasarathy S, Grasse BJ, Miller E, Steinberg D, Witztum JL. Effects of oleate-rich and linoleate-rich diets on the susceptibility of low density lipoprotein to oxidative modification in mildly hypercholesterolemic subjects. J Clin Invest. 1993;91(2):668-76. doi:10.1172/JCI116247 | Intervention/Exposure
1921 | Rebholz CM, Crews DC, Grams ME, et al. DASH (Dietary Approaches to Stop Hypertension) diet and risk of subsequent kidney disease. Am J Kidney Dis. 2016;68(6):853-861. doi:10.1053/j.ajkd.2016.05.019 | Outcome
1922 | Rebholz CM, Reynolds K, Wofford MR, et al. Effect of soybean protein on novel cardiovascular disease risk factors: a randomized controlled trial. Eur J Clin Nutr. 2013;67(1):58-63. doi:10.1038/ejcn.2012.186 | Intervention/Exposure; Comparator
1923 | Redondo N, Garcia-Gonzalez N, Diaz-Prieto LE, et al. Effects of ewe’s milk yogurt (whole and semi-skimmed) and cow’s milk yogurt on inflammation markers and gut microbiota of subjects with borderline-high plasma cholesterol levels: A crossover study. Eur J Nutr. 2019;58(3):1113-1124. doi:10.1007/s00394-018-1626-0 | Outcome
1924 | Regulska-Ilow B, Ilow R, Kawicka A, et al. Evaluation of fatty acids daily intake and diets atherogenicity of dietetics students of Wroclaw Medical University. Rocz Panstw Zakl Hig. 2013;64(3):183-90. | Study design; Intervention/Exposure
1925 | Reidlinger DP, Darzi J, Hall WL, et al. How effective are current dietary guidelines for cardiovascular disease prevention in healthy middle-aged and older men and women? A randomized controlled trial. Am J Clin Nutr. 2015;101(5):922-30. doi:10.3945/ajcn.114.097352 | Intervention/Exposure
1926 | Reimer R. Milk product intake: implications for weight control and type 2 diabetes. Can Nurse. 2008;104(5):20. | Study design; Publication status
1927 | Reimers TM, Brown KM, Van Horn L, et al. Maternal acceptability of a dietary intervention designed to lower children’s intake of saturated fat and cholesterol: the Dietary Intervention Study in Children (DISC). J Am Diet Assoc. 1998;98(1):31-4. doi:10.1016/s0002-8223(98)00010-8 | Intervention/Exposure; Population
1928 | Renaud S, de Lorgeril M, Delaye J, et al. Cretan Mediterranean diet for prevention of coronary heart disease. Am J Clin Nutr. 1995;61(6 Suppl):1360S-1367S. doi:10.1093/ajcn/61.6.1360S | Intervention/Exposure; Health status
1929 | Rentsch CT, Garfield V, Mathur R, et al. Sex-specific risks for cardiovascular disease across the glycaemic spectrum: a population-based cohort study using the UK Biobank. Lancet Reg Health Eur. 2023;32:100693. doi:10.1016/j.lanepe.2023.100693 | Intervention/Exposure
1930 | Retterstøl K, Svendsen M, Narverud I, Holven KB. Effect of low carbohydrate high fat diet on LDL cholesterol and gene expression in normal-weight, young adults: A randomized controlled study. Atherosclerosis. 2018;279:52-61. doi:10.1016/j.atherosclerosis.2018.10.013 | Duration
1931 | Revilla I, Santos S, Hernandez-Jimenez M, Vivar-Quintana AM. The effects of the progressive replacement of meat with texturized pea protein in low-fat frankfurters made with olive oil. Foods. 2022;11(7)doi:10.3390/foods11070923 | Outcome
1932 | Reyes-Garcia R, Mendoza N, Palacios S, et al. Effects of daily intake of calcium and vitamin D-enriched milk in healthy postmenopausal women: A randomized, controlled, double-blind nutritional study. J Womens Health (Larchmt). 2018;27(5):561-568. doi:10.1089/jwh.2017.6655 | Intervention/Exposure; Comparator
1933 | Rey-García J, Guallar-Castillón P, Donat-Vargas C, et al. Fried-food consumption does not increase the risk of stroke in the Spanish cohort of the European Prospective Investigation into Cancer and Nutrition (EPIC) study. J Nutr. 2020;150(12):3241-3248. doi:10.1093/jn/nxaa272 | Intervention/Exposure
1934 | Reyna N, Reyna E, Bermudez V, et al. “Ingestion of lean beef meats in blood pressure and biochemical parameters in hypertensives patients". Revista Latinoamericana De Hipertension. 2009;4(1):26-31. | Study design; Sample size/Power
1935 | Reynolds KD, Gillum JL, Hyman DJ, et al. Comparing two strategies to modify dietary behavior and serum cholesterol. J Cardiovasc Risk. 1997;4(1):1-5. doi:10.1177/174182679700400101 | Intervention/Exposure
1936 | Rezende LF, Azeredo CM, Canella DS, Luiz Odo C, Levy RB, Eluf-Neto J. Coronary heart disease mortality, cardiovascular disease mortality and all-cause mortality attributable to dietary intake over 20years in Brazil. Int J Cardiol. 2016;217:64-8. doi:10.1016/j.ijcard.2016.04.176 | Comparator
1937 | Rezende-Alves K, Hermsdorff HHM, Miranda A, et al. Effects of minimally and ultra-processed foods on blood pressure in Brazilian adults: a two-year follow up of the CUME Project. J Hypertens. 2023;41(1):122-131. doi:10.1097/HJH.0000000000003311 | Intervention/Exposure
1938 | Rhodes KS, Bookstein LC, Aaronson LS, Mercer NM, Orringer CE. Intensive nutrition counseling enhances outcomes of National Cholesterol Education Program dietary therapy. J Am Diet Assoc. 1996;96(10):1003-10; quiz 1011-2. doi:10.1016/S0002-8223(96)00268-4 | Intervention/Exposure
1939 | Ribas SA, Paravidino VB, Brandao JM, Santana da Silva LC. The cardiovascular health integrated lifestyle diet (CHILD) lowers LDL-cholesterol levels in Brazilian dyslipidemic pediatric patients. J Am Nutr Assoc. 2022;41(4):352-359. doi:10.1080/07315724.2021.1887006 | Intervention/Exposure
1940 | Ribas SA, Sichieri R, Moreira ASB, et al. Phytosterol-enriched milk lowers LDL-cholesterol levels in Brazilian children and adolescents: Double-blind, cross-over trial. Nutr Metab Cardiovasc Dis. 2017;S0939-4753(17)30225-9. doi:10.1016/j.numecd.2017.09.010 | Intervention/Exposure; Sample size/Power
1941 | Ricci C, Baumgartner J, Zec M, Kruger HS, Smuts CM. Type of dietary fat intakes in relation to all-cause and cause-specific mortality in US adults: an iso-energetic substitution analysis from the American National Health and Nutrition Examination Survey linked to the US mortality registry. Br J Nutr. 2018;119(4):456-463. doi:10.1017/S0007114517003889 | Intervention/Exposure
1942 | Richard C, Royer MM, Couture P, et al. Effect of the Mediterranean diet on plasma adipokine concentrations in men with metabolic syndrome. Metabolism. 2013;62(12):1803-10. doi:10.1016/j.metabol.2013.07.012 | Intervention/Exposure; Outcome
1943 | Richardson BE, Baird DD. A study of milk and calcium supplement intake and subsequent preeclampsia in a cohort of pregnant women. Am J Epidemiol. 1995;141(7):667-73. doi:10.1093/oxfordjournals.aje.a117483 | Study design; Outcome
1944 | Richelsen B, Agerbaek M, Gerdes LU. Cholesterol-lowering effect of a new fermented milk product in healthy 44-year old Danish men. Ugeskr Laeger. 1993;155(38):3015-9. | Publication language
1945 | Richelsen B, Kristensen K, Pedersen SB. Long-term (6 months) effect of a new fermented milk product on the level of plasma lipoproteins-a placebo-controlled and double blind study. Eur J Clin Nutr. 1996;50(12):811-5. | Comparator
1946 | Rideout TC, Chan YM, Harding SV, Jones PJ. Low and moderate-fat plant sterol fortified soymilk in modulation of plasma lipids and cholesterol kinetics in subjects with normal to high cholesterol concentrations: report on two randomized crossover studies. Lipids Health Dis. 2009;8:45. doi:10.1186/1476-511X-8-45 | Comparator
1947 | Rideout TC, Marinangeli CP, Martin H, Browne RW, Rempel CB. Consumption of low-fat dairy foods for 6 months improves insulin resistance without adversely affecting lipids or bodyweight in healthy adults: a randomized free-living cross-over study. Nutr J. 2013;12:56. doi:10.1186/1475-2891-12-56 | Intervention/Exposure; Comparator
1948 | Ridges L, Sunderland R, Moerman K, Meyer B, Astheimer L, Howe P. Cholesterol lowering benefits of soy and linseed enriched foods. Asia Pac J Clin Nutr. 2001;10(3):204-11. doi:10.1046/j.1440-6047.2001.00253.x | Study design; Intervention/Exposure
1949 | Ried K, Frank OR, Stocks NP. Dark chocolate or tomato extract for prehypertension: a randomised controlled trial. BMC Complement Altern Med. 2009;9:22. doi:10.1186/1472-6882-9-22 | Comparator
1950 | Rietsema S, Eelderink C, Joustra ML, et al. Effect of high compared with low dairy intake on blood pressure in overweight middle-aged adults: results of a randomized crossover intervention study. Am J Clin Nutr. 2019;110(2):340-348. doi:10.1093/ajcn/nqz116 | Intervention/Exposure; Comparator
1951 | Rimm EB, Ascherio A, Giovannucci E, Spiegelman D, Stampfer MJ, Willett WC. Vegetable, fruit, and cereal fiber intake and risk of coronary heart disease among men. JAMA. 1996;275(6):447-51. doi:10.1001/jama.1996.03530300031036 | Intervention/Exposure
1952 | Rinott E, Meir AY, Tsaban G, et al. The effects of the Green-Mediterranean diet on cardiometabolic health are linked to gut microbiome modifications: a randomized controlled trial. Genome Med. 2022;14(1):29. doi:10.1186/s13073-022-01015-z | Intervention/Exposure; Comparator
1953 | Riseberg E, Lopez-Cepero A, Mangano KM, Tucker KL, Mattei J. Specific dietary protein sources are associated with cardiometabolic risk factors in the Boston Puerto Rican Health Study. J Acad Nutr Diet. 2022;122(2):298-308 e3. doi:10.1016/j.jand.2021.05.020 | Comparator
1954 | Risérus U. Cardiovascular disease. World Rev Nutr Diet. 2015;111:94-9. doi:10.1159/000362305 | Publication status
1955 | Rivas M, Garay RP, Escanero JF, Cia P, Jr., Cia P, Alda JO. Soy milk lowers blood pressure in men and women with mild to moderate essential hypertension. J Nutr. 2002;132(7):1900-2. doi:10.1093/jn/132.7.1900 | Health status; Sample size/Power
1956 | Rivellese AA, Maffettone A, Vessby B, et al. Effects of dietary saturated, monounsaturated and n-3 fatty acids on fasting lipoproteins, LDL size and post-prandial lipid metabolism in healthy subjects. Atherosclerosis. 2003;167(1):149-58. doi:10.1016/s0021-9150(02)00424-0 | Intervention/Exposure; Duration
1957 | Robinson DM, Martin NC, Robinson LE, Ahmadi L, Marangoni AG, Wright AJ. Influence of interesterification of a stearic acid-rich spreadable fat on acute metabolic risk factors. Lipids. 2009;44(1):17-26. doi:10.1007/s11745-008-3253-7 | Sample size/Power
1958 | Robinson SM, Batelaan SF, Syddall HE, et al. Combined effects of dietary fat and birth weight on serum cholesterol concentrations: the Hertfordshire Cohort Study. Am J Clin Nutr. 2006;84(1):237-44. doi:10.1093/ajcn/84.1.237 | Intervention/Exposure
1959 | Roche H, Gibney MJ. The effect of consumption of fish oil-enriched spreadable fats on platelet phospholipid fatty acid composition in human volunteers. Int J Vitam Nutr Res. 1994;64(3):237-42. | Sample size/Power
1960 | Roche HM, Zampelas A, Knapper JM, et al. Effect of long-term olive oil dietary intervention on postprandial triacylglycerol and factor VII metabolism. Am J Clin Nutr. 1998;68(3):552-60. doi:10.1093/ajcn/68.3.552 | Sample size/Power
1961 | Rock CL, Flatt SW, Pakiz B, et al. Effects of diet composition on weight loss, metabolic factors and biomarkers in a 1-year weight loss intervention in obese women examined by baseline insulin resistance status. Metabolism. 2016;65(11):1605-1613. doi:10.1016/j.metabol.2016.07.008 | Intervention/Exposure
1962 | Rock CL, Flatt SW, Pakiz B, et al. Weight loss, glycemic control, and cardiovascular disease risk factors in response to differential diet composition in a weight loss program in type 2 diabetes: A randomized controlled trial. Diabetes Care. 2014;37(6):1573-80. doi:10.2337/dc13-2900 | Intervention/Exposure; Health status
1963 | Rock CL, Flatt SW, Thomson CA, et al. Plasma triacylglycerol and HDL cholesterol concentrations confirm self-reported changes in carbohydrate and fat intakes in women in a diet intervention trial. J Nutr. 2004;134(2):342-7. doi:10.1093/jn/134.2.342 | Intervention/Exposure
1964 | Rodenas S, Rodriguez-Gil S, Merinero MC, Sanchez-Muniz FJ. Dietary exchange of an olive oil and sunflower oil blend for extra virgin olive oil decreases the estimate cardiovascular risk and LDL and apolipoprotein AII concentrations in postmenopausal women. J Am Coll Nutr. 2005;24(5):361-9. doi:10.1080/07315724.2005.10719486 | Study design; Sample size/Power
1965 | Roderick P, Ruddock V, Hunt P, Miller G. A randomized trial to evaluate the effectiveness of dietary advice by practice nurses in lowering diet-related coronary heart disease risk. Br J Gen Pract. 1997;47(414):7-12. | Intervention/Exposure
1966 | Rodríguez Artalejo F, Banegas JR, Garcia Colmenero C, del Rey Calero J. Lower consumption of wine and fish as a possible explanation for higher ischaemic heart disease mortality in Spain’s Mediterranean region. Int J Epidemiol. 1996;25(6):1196-201. doi:10.1093/ije/25.6.1196 | Intervention/Exposure; Comparator
1967 | Rodriguez-Cano A, Mier-Cabrera J, Balas-Nakash M, Munoz-Manrique C, Legorreta-Legorreta J, Perichart-Perera O. Dietary changes associated with improvement of metabolic syndrome components in postmenopausal women receiving two different nutrition interventions. Menopause. 2015;22(7):758-64. doi:10.1097/GME.0000000000000400 | Comparator
1968 | Rodriguez-Moran M, Guerrero-Romero F, Rascon-Pacheco RA, Multidisciplinary Research Group on Diabetes of the Instituto Mexicano del Seguro S. Dietary factors related to the increase of cardiovascular risk factors in traditional Tepehuanos communities from Mexico. A 10 year follow-up study. Nutr Metab Cardiovasc Dis. 2009;19(6):409-16. doi:10.1016/j.numecd.2008.08.005 | Intervention/Exposure; Country
1969 | Rogers IS, Emmett PM, Team AS. Fat content of the diet among preschool children in southwest Britain: II. Relationship with growth, blood lipids, and iron status. Pediatrics. 2001;108(3):e49. doi:10.1542/peds.108.3.e49 | Intervention/Exposure
1970 | Rogerson D, Macas D, Milner M, Liu Y, Klonizakis M. Contrasting effects of short-term Mediterranean and vegan diets on microvascular function and cholesterol in younger adults: A comparative pilot study. Nutrients. 2018;10(12):1897. doi:10.3390/nu10121897 | Sample size/Power
1971 | Rohrmann S, Overvad K, Bueno-de-Mesquita HB, et al. Meat consumption and mortality-results from the European Prospective Investigation into Cancer and Nutrition. BMC Med. 2013;11:63. doi:10.1186/1741-7015-11-63 | Comparator
1972 | Romeo J, Warnberg J, Garcia-Marmol E, et al. Daily consumption of milk enriched with fish oil, oleic acid, minerals and vitamins reduces cell adhesion molecules in healthy children. Nutr Metab Cardiovasc Dis. 2011;21(2):113-20. doi:10.1016/j.numecd.2009.08.007 | Comparator
1973 | Root M, Collier SR, Zwetsloot KA, West KL, McGinn MC. A randomized trial of fish oil omega-3 fatty acids on arterial health, inflammation, and metabolic syndrome in a young healthy population. Nutr J. 2013;12:40. doi:10.1186/1475-2891-12-40 | Intervention/Exposure
1974 | Rosado JL, Garcia OP, Ronquillo D, et al. Intake of milk with added micronutrients increases the effectiveness of an energy-restricted diet to reduce body weight: a randomized controlled clinical trial in Mexican women. J Am Diet Assoc. 2011;111(10):1507-16. doi:10.1016/j.jada.2011.07.011 | Intervention/Exposure; Comparator
1975 | Rosamond WD, Ammerman AS, Holliday JL, et al. Cardiovascular disease risk factor intervention in low-income women: the North Carolina WISEWOMAN project. Prev Med. 2000;31(4):370-9. doi:10.1006/pmed.2000.0726 | Intervention/Exposure
1976 | Rosengren A, Stegmayr B, Johansson I, Huhtasaari F, Wilhelmsen L. Coronary risk factors, diet and vitamins as possible explanatory factors of the Swedish north-south gradient in coronary disease: a comparison between two MONICA centres. J Intern Med. 1999;246(6):577-586. doi:10.1046/j.1365-2796.1999.00616.x | Study design; Intervention/Exposure
1977 | Rossi EA, Vendramini RC, Carlos IZ, de Oliveira MG, de Valdez GF. Effect of a new fermented soy milk product on serum lipid levels in normocholesterolemic adult men. Arch Latinoam Nutr. 2003;53(1):47-51. | Publication language; Comparator
1978 | Rossi F, Alberto B, Capraro J, Simona B. Diets containing dairy foods positively affects weight and fat loss and cytokines blood levels in premenopausal obese women. Med J Nutr Metab. 2015;8(2):165-174. doi:10.3233/Mnm-150035 | Outcome; Sample size/Power
1979 | Roswall N, Sandin S, Löf M, et al. Adherence to the healthy Nordic food index and total and cause-specific mortality among Swedish women. Eur J Epidemiol. 2015;30(6):509-517. doi:10.1007/s10654-015-0021-x | Intervention/Exposure
1980 | Roughead ZK, Hunt JR, Johnson LK, Badger TM, Lykken GI. Controlled substitution of soy protein for meat protein: Effects on calcium retention, bone, and cardiovascular health indices in postmenopausal women. J Clin Endocrinol Metab. 2005;90(1):181-9. doi:10.1210/jc.2004-0393 | Intervention/Exposure; Sample size/Power
1981 | Roussell MA, Hill AM, Gaugler TL, et al. Beef in an optimal lean diet study: Effects on lipids, lipoproteins, and apolipoproteins. Am J Clin Nutr. 2012;95(1):9-16. doi:10.3945/ajcn.111.016261 | Intervention/Exposure
1982 | Roussell MA, Hill AM, Gaugler TL, et al. Effects of a DASH-like diet containing lean beef on vascular health. J Hum Hypertens. 2014;28(10):600-5. doi:10.1038/jhh.2014.34 | Duplicate
1983 | Roy SJ, Fico BG, Baker BD, et al. Effects of full-fat dairy products on subclinical vascular function in adults with elevated blood pressure: A randomized clinical trial. Eur J Clin Nutr. 2020;74(1):9-16. doi:10.1038/s41430-019-0435-8 | Outcome
1984 | Różańska D, Kujawa K, Szuba A, et al. Dietary patterns and the prevalence of noncommunicable diseases in the PURE Poland study participants. Nutrients. 2023;15(16):3524. doi:10.3390/nu15163524 | Intervention/Exposure
1985 | Rozanski A, Arnson Y, Gransar H, et al. Relation of intake of saturated fat to atherosclerotic risk factors, health behaviors, coronary atherosclerosis, and all-cause mortality among patients who underwent coronary artery calcium scanning. Am J Cardiol. 2021;138:40-45. doi:10.1016/j.amjcard.2020.10.014 | Intervention/Exposure
1986 | Rozati M, Barnett J, Wu D, et al. Cardio-metabolic and immunological impacts of extra virgin olive oil consumption in overweight and obese older adults: A randomized controlled trial. Nutr Metab (Lond). 2015;12:28. doi:10.1186/s12986-015-0022-5 | Intervention/Exposure; Sample size/Power
1987 | Ru Y, Wang N, Min Y, et al. Characterization of dietary patterns and assessment of their relationships with metabolomic profiles: A community-based study. Clin Nutr. 2021;40(5):3531-3541. doi:10.1016/j.clnu.2020.12.006 | Intervention/Exposure
1988 | Ruan Y, Huang Y, Zhang Q, Qin S, Du X, Sun Y. Association between dietary patterns and hypertension among Han and multi-ethnic population in southwest China. BMC Public Health. Sep 10 2018;18(1):1106. doi:10.1186/s12889-018-6003-7 | Study design
1989 | Rubio-Martin E, Garcia-Escobar E, Ruiz de Adana MS, et al. Comparison of the Effects of Goat Dairy and Cow Dairy Based Breakfasts on Satiety, Appetite Hormones, and Metabolic Profile. Nutrients. Aug 15 2017;9(8)doi:10.3390/nu9080877 | Duration
1990 | Rudkowska I, AbuMweis SS, Nicolle C, Jones PJH. Cholesterol-lowering efficacy of plant sterols in low-fat yogurt consumed as a snack or with a meal. J Am Coll Nutr. 2008;27(5):588-595. doi:10.1080/07315724.2008.10719742 | Intervention/Exposure; Sample size/Power
1991 | Rudolph TK, Ruempler K, Schwedhelm E, et al. Acute effects of various fast-food meals on vascular function and cardiovascular disease risk markers: the Hamburg Burger Trial. Am J Clin Nutr. 2007;86(2):334-340. doi:10.1093/ajcn/86.2.334 | Duration
1992 | Rueda JM, Khosla P. Impact of breakfasts (with or without eggs) on body weight regulation and blood lipids in university students over a 14-week semester. Nutrients. 2013;5(12):5097-113. doi:10.3390/nu5125097 | Intervention/Exposure
1993 | Ruel G, Shi ZM, Zhen SQ, et al. Association between nutrition and the evolution of multimorbidity: The importance of fruits and vegetables and whole grain products. Clin Nutr. 2014;33(3):513-520. doi:10.1016/j.clnu.2013.07.009 | Intervention/Exposure; Outcome
1994 | Ruggiero E, Di Castelnuovo A, Costanzo S, et al. Incremental monounsaturated to saturated fat ratio and fibre consumption is associated with a reduction in a composite score of modifiable cardiovascular risk factors: Prospective results from the Moli-sani study. Eur J Clin Nutr. Dec 2022;76(12):1697-1704. doi:10.1038/s41430-022-01185-4 | Intervention/Exposure
1995 | Ruggiero E, Di Castelnuovo A, Costanzo S, et al. Incremental monounsaturated to saturated fat ratio and fibre consumption is associated with a reduction in a composite score of modifiable cardiovascular risk factors: Prospective results from the Moli-sani study. Eur J Clin Nutr. 2022;76(12):1697-1704. doi:10.1038/s41430-022-01185-4 | Intervention/Exposure
1996 | Ruidavets JB, Bongard V, Dallongeville J, et al. High consumptions of grain, fish, dairy products and combinations of these are associated with a low prevalence of metabolic syndrome. J Epidemiol Community Health. 2007;61(9):810-7. doi:10.1136/jech.2006.052126 | Study design; Outcome
1997 | Ruiz-Gutierrez V, Morgado N, Prada JL, Perez-Jimenez F, Muriana FJ. Composition of human VLDL triacylglycerols after ingestion of olive oil and high oleic sunflower oil. J Nutr. 1998;128(3):570-6. doi:10.1093/jn/128.3.570 | Intervention/Exposure; Sample size/Power
1998 | Ruiz-Gutiérrez V, Muriana FJG, Guerrero A, Cert AM, Villar J. Role of dietary oleic acid from two different sources on fatty acid composition of erythrocyte membrane and blood pressure in healthy subjects. J Nutr Biochem. 1997;8(12):689-695. doi:10.1016/S0955-2863(97)00120-4 | Intervention/Exposure
1999 | Ruiz-Gutiérrez V, Muriana FJG, Guerrero A, Villar J. Olive oil and high-oleic sunflower oil on human plasma and erythrocyte membrane lipids. J Hypertens. 1996;14(12):1483-90. doi:10.1097/00004872-199612000-00016 | Intervention/Exposure
2000 | Ruiz-Gutiérrez V, Perona JS, Pacheco YM, Muriana FJG, Villar J. Incorporation of dietary triacylglycerols from olive oil and high-oleic sunflower oil into VLDL triacylglycerols of hypertensive patients. Eur J Clin Nutr. 1999;53(9):687-693. doi:10.1038/sj.ejcn.1600833 | Sample size/Power
2001 | Ruiz-Núñez B, Kuipers RS, Luxwolda MF, et al. Saturated fatty acid (SFA) status and SFA intake exhibit different relations with serum total cholesterol and lipoprotein cholesterol: A mechanistic explanation centered around lifestyle-induced low-grade inflammation. J Nutr Biochem. Mar 2014;25(3):304-12. doi:10.1016/j.jnutbio.2013.11.004 | Intervention/Exposure; Country
2002 | Rumpler WV, Clevidence BA, Muesing RA, Rhodes DG. Changes in women’s plasma lipid and lipoprotein concentrations due to moderate consumption of alcohol are affected by dietary fat level. J Nutr. 1999;129(9):1713-1717. doi:10.1093/jn/129.9.1713 | Intervention/Exposure
2003 | Ruth MR, Port AM, Shah M, et al. Consuming a hypocaloric high fat low carbohydrate diet for 12 weeks lowers C-reactive protein, and raises serum adiponectin and high density lipoprotein-cholesterol in obese subjects. Metabolism. 2013;62(12):1779-87. doi:10.1016/j.metabol.2013.07.006 | Intervention/Exposure
2004 | Rylander L, Hagmar L. Mortality and cancer incidence among women with a high consumption of fatty fish contaminated with persistent organochlorine compounds. Scand J Work Environ Health. 1995;21(6):419-426. doi:10.5271/sjweh.57 | Intervention/Exposure
2005 | Rywik SL, Piotrowski W, Rywik TM, Broda G, Szcześniewska D. Is the decrease of cardiovascular mortality in Poland associated with the reduction of global cardiovascular risk related to changes in life style? Kardiol Pol. 2003;58(5):344-55;discussion:355. | Intervention/Exposure
2006 | Saarinen HJ, Sittiwet C, Simonen P, et al. Determining the mechanisms of dietary turnip rapeseed oil on cholesterol metabolism in men with metabolic syndrome. J Investig Med. 2018;66(1):11-16. doi:10.1136/jim-2017-000495 | Outcome
2007 | Sabaté J, Fraser GE, Burke K, Knutsen SF, Bennett H, Lindsted KD. Effects of walnuts on serum lipid levels and blood pressure in normal men. N Engl J Med. 1993;328(9):603-7. doi:10.1056/NEJM199303043280902 | Intervention/Exposure; Sample size/Power
2008 | Sabour H, Norouzi-Javidan A, Soltani Z, et al. The correlation between dietary fat intake and blood pressure among people with spinal cord injury. Iran J Neurol. 2016;15(3):121-7. | Intervention/Exposure; Health status
2009 | Sacerdote C, Fiorini L, Rosato R, Audenino M, Valpreda M, Vineis P. Randomized controlled trial: Effect of nutritional counselling in general practice. Int J Epidemiol. 2006;35(2):409-15. doi:10.1093/ije/dyi170 | Intervention/Exposure
2010 | Sacks FM, Svetkey LP, Vollmer WM, et al. Effects on blood pressure of reduced dietary sodium and the Dietary Approaches to Stop Hypertension (DASH) diet. DASH-Sodium Collaborative Research Group. N Engl J Med. 2001;344(1):3-10. doi:10.1056/NEJM200101043440101 | Intervention/Exposure
2011 | Sadeghi M, Simani M, Mohammadifard N, et al. Longitudinal association of dietary fat intake with cardiovascular events in a prospective cohort study in Eastern Mediterranean region. Int J Food Sci Nutr. 2021;72(8):1095-1104. doi:10.1080/09637486.2021.1895725 | Comparator
2012 | Saedi S, Noroozi M, Khosrotabar N, Mazandarani S, Ghadrdoost B. How canola and sunflower oils affect lipid profile and anthropometric parameters of participants with dyslipidemia. Med J Islam Repub Iran. 2017;31:5. doi:10.18869/mjiri.31.5 | Intervention/Exposure
2013 | Sahay RD, Couch SC, Missoni S, et al. Dietary patterns in adults from an Adriatic Island of Croatia and their associations with metabolic syndrome and its components. Coll Antropol. 2013;37(2):335-42. | Study design
2014 | Saito E, Tang X, Abe SK, et al. Association between meat intake and mortality due to all-cause and major causes of death in a Japanese population. PLoS One. 2020;15(12):e0244007. doi:10.1371/journal.pone.0244007 | Comparator
2015 | Salamone D, Annuzzi G, Vessby B, et al. Fatty acid composition of cholesterol esters reflects dietary fat intake after dietary interventions in a multinational population. J Clin Lipidol. 2023;17(4):466-474. doi:10.1016/j.jacl.2023.05.095 | Intervention/Exposure; Outcome
2016 | Saleh-Ghadimi S, Kheirouri S, Golmohammadi A, Moludi J, Jafari-Vayghan H, Alizadeh M. Effect of flaxseed oil supplementation on anthropometric and metabolic indices in patients with coronary artery disease: A double-blinded randomized controlled trial. J Cardiovasc Thorac Res. 2019;11(2):152-160. doi:10.15171/jcvtr.2019.26 | Health status
2017 | Sales RL, Coelho SB, Costa NMB, et al. The effects of peanut oil on lipid profile of normolipidemic adults: A three-country collaborative study. J Appl Res. 2008;8(3):216-225. | Intervention/Exposure; Country
2018 | Saliu MA, Salihu A, Mada SB, Owolabi OA. Dyslipidaemia-related cardiovascular risk among pregnant women attending Aminu Kano Teaching Hospital Kano: A longitudinal study. J Taibah Univ Med Sci. 2021;16(6):870-877. doi:10.1016/j.jtumed.2021.07.004 | Country
2019 | Sallinen T, Viitasalo A, Lintu N, et al. The effects of an 8-year individualised lifestyle intervention on food consumption and nutrient intake from childhood to adolescence: the PANIC Study. J Nutr Sci. 2022;11:e40. doi:10.1017/jns.2022.13 | Intervention/Exposure; Outcome
2020 | Salo P, Kuusisto P. Cholesterol lowering effect of plant stanol ester yoghurt drinks with added camelina oil. Cholesterol. 2016;2016:5349389. doi:10.1155/2016/5349389 | Comparator; Sample size/Power
2021 | Salo P, Seppanen-Laakso T, Laakso I, et al. Low-saturated fat, low-cholesterol diet in 3-year-old children: effect on intake and composition of trans fatty acids and other fatty acids in serum phospholipid fraction-The STRIP study. Special Turku coronary Risk factor Intervention Project for children. J Pediatr. 2000;136(1):46-52. doi:10.1016/s0022-3476(00)90048-9 | Intervention/Exposure
2022 | Salo P, Viikari J, Hämäläinen M, et al. Fatty acid composition of serum cholesterol esters as a reflector of low-saturated-fat, low-cholesterol diet in young children: the STRIP project. The Special Turku coronary Risk factor Intervention Project. Acta Paediatr. 2000;89(4):399-405. doi:10.1080/080352500750028087 | Population
2023 | Salo P, Viikari J, Rask-Nissila L, et al. Effect of low-saturated fat, low-cholesterol dietary intervention on fatty acid compositions in serum lipid fractions in 5-year-old children. The STRIP project. Eur J Clin Nutr. 1999;53(12):927-32. doi:10.1038/sj.ejcn.1600872 | Intervention/Exposure
2024 | Samara A, Herbeth B, Ndiaye NC, et al. Dairy product consumption, calcium intakes, and metabolic syndrome-related factors over 5 years in the STANISLAS study. Nutrition. 2013;29(3):519-24. doi:10.1016/j.nut.2012.08.013 | Comparator
2025 | Samieri C, Feart C, Proust-Lima C, et al. Olive oil consumption, plasma oleic acid, and stroke incidence: the Three-City Study. Neurology. 2011;77(5):418-25. doi:10.1212/WNL.0b013e318220abeb | Intervention/Exposure
2026 | Samman S, Lai NT, Sullivan DR. The effect of a lipid-lowering diet on plasma lipids and lipoproteins in mildly hypercholesterolaemic subjects: a potential role for occasional treats. J Nutr Biochem. 2000;11(5):250-4. doi:10.1016/s0955-2863(00)00072-3 | Sample size/Power
2027 | Samuelson G, Bratteby LE, Mohsen R, Vessby B. Dietary fat intake in healthy adolescents: inverse relationships between the estimated intake of saturated fatty acids and serum cholesterol. Br J Nutr. 2001;85(3):333-341. doi:10.1079/Bjn2000279 | Study design; Intervention/Exposure
2028 | Sánchez-Muniz FJ, Bastida S, Cuesta C, Domingo A. Lipaemia and lipoproteinaemia in a Spanish male nonsmoker population consuming sunflower oil. Z Ernahrungswiss. 1996;35(3):259-65. doi:10.1007/BF01625690 | Duration
2029 | Sánchez-Muniz FJ, Carbajal A, Rodenas S, et al. Nutritional assessment, health markers and lipoprotein profile in postmenopausal women belonging to a closed community. Eur J Clin Nutr. 2003;57 Suppl 1:S26-30. doi:10.1038/sj.ejcn.1601806 | Study design
2030 | Sanchez-Muniz FJ, Merinero MC, Rodriguez-Gil S, Ordovas JM, Rodenas S, Cuesta C. Dietary fat saturation affects apolipoprotein AII levels and HDL composition in postmenopausal women. J Nutr. 2002;132(1):50-4. doi:10.1093/jn/132.1.50 | Sample size/Power
2031 | Sanchez-Muniz FJ, Oubina P, Rodenas S, Benedi J, Cuesta C. Platelet aggregation, thromboxane production and thrombogenic ratio in postmenopausal women consuming high oleic acid-sunflower oil or palmolein. Eur J Nutr. 2003;42(6):299-306. doi:10.1007/s00394-003-0429-z | Sample size/Power
2032 | Sander R. Benefits of dark chocolate in treating metabolic syndrome. Nurs Older People. 2012;24(7):11. doi:10.7748/nop.24.7.11.s9 | Study design; Publication status
2033 | Sanders TA, Lewis FJ, Goff LM, Chowienczyk PJ, Group RS. SFAs do not impair endothelial function and arterial stiffness. Am J Clin Nutr. 2013;98(3):677-83. doi:10.3945/ajcn.113.063644 | Intervention/Exposure
2034 | Saneei P, Hashemipour M, Kelishadi R, Esmaillzadeh A. The Dietary Approaches to Stop Hypertension (DASH) diet affects inflammation in childhood metabolic syndrome: a randomized cross-over clinical trial. Ann Nutr Metab. 2014;64(1):20-7. doi:10.1159/000358341 | Intervention/Exposure
2035 | Saneei P, Hashemipour M, Kelishadi R, Rajaei S, Esmaillzadeh A. Effects of recommendations to follow the Dietary Approaches to Stop Hypertension (DASH) diet v. usual dietary advice on childhood metabolic syndrome: a randomised cross-over clinical trial. Br J Nutr. 2013;110(12):2250-9. doi:10.1017/S0007114513001724 | Intervention/Exposure
2036 | Santiago S, Sayon-Orea C, Babio N, et al. Yogurt consumption and abdominal obesity reversion in the PREDIMED study. Nutr Metab Cardiovasc Dis. 2016;26(6):468-75. doi:10.1016/j.numecd.2015.11.012 | Outcome
2037 | Santo AS, Santo AM, Browne RW, et al. Postprandial lipemia detects the effect of soy protein on cardiovascular disease risk compared with the fasting lipid profile. Lipids. 2010;45(12):1127-38. doi:10.1007/s11745-010-3487-z | Intervention/Exposure; Duration
2038 | Santos MS, Lichtenstein AH, Leka LS, Goldin B, Schaefer EJ, Meydani SN. Immunological effects of low-fat diets with and without weight loss. J Am Coll Nutr. 2003;22(2):174-82. doi:10.1080/07315724.2003.10719291 | Sample size/Power
2039 | Santurino C, Lopez-Plaza B, Fontecha J, et al. Consumption of goat cheese naturally rich in omega-3 and conjugated linoleic acid improves the cardiovascular and inflammatory biomarkers of overweight and obese subjects: A randomized controlled trial. Nutrients. 2020;12(5):1315. doi:10.3390/nu12051315 | Comparator; Sample size/Power
2040 | Sapp PA, Kris-Etherton PM, Petersen KS. Peanuts or an isocaloric lower fat, higher carbohydrate nighttime snack have similar effects on fasting glucose in adults with elevated fasting glucose concentrations: A 6-week randomized crossover trial. J Nutr. 2022;152(1):153-162. doi:10.1093/jn/nxab347 | Intervention/Exposure
2041 | Saracci R. The dietary prevention of ischaemic heart disease. IARC Sci Publ. 2002;156:531-3. | Study design
2042 | Sarapis K, Thomas CJ, Hoskin J, et al. The effect of high polyphenol extra virgin olive oil on blood pressure and arterial stiffness in healthy Australian adults: A randomized, controlled, cross-over study. Nutrients. 2020;12(8):2272. doi:10.3390/nu12082272 | Intervention/Exposure; Comparator
2043 | Sarebanhassanabadi M, Mirhosseini SJ, Mirzaei M, et al. Association between dietary habits and changes in cardiometabolic risk factors in patients with metabolic syndrome: A 10-year follow-up study. Prog Nutr. 2019;21:348-358. doi:10.23751/pn.v21i1-S.6493 | Comparator
2044 | Saris WH. The fat/carbohydrate ratio in the diet-implications for a healthy diet. Int Dent J. 2001;51(6 Suppl 1):407. doi:10.1111/j.1875-595x.2001.tb00587.x | Study design
2045 | Sarkkinen E, Korhonen M, Erkkila A, Ebeling T, Uusitupa M. Effect of apolipoprotein E polymorphism on serum lipid response to the separate modification of dietary fat and dietary cholesterol. Am J Clin Nutr. 1998;68(6):1215-22. doi:10.1093/ajcn/68.6.1215 | Intervention/Exposure
2046 | Sarkkinen ES, Uusitupa MI, Gylling H, Miettinen TA. Fat-modified diets influence serum concentrations of cholesterol precursors and plant sterols in hypercholesterolemic subjects. Metabolism. 1998;47(6):744-50. doi:10.1016/s0026-0495(98)90040-3 | Intervention/Exposure; Comparator
2047 | Sarkkinen ES, Uusitupa MI, Pietinen P, et al. Long-term effects of three fat-modified diets in hypercholesterolemic subjects. Atherosclerosis. 1994;105(1):9-23. doi:10.1016/0021-9150(94)90003-5 | Intervention/Exposure
2048 | Sarriá B, Martínez-López S, Sierra-Cinos JL, García-Diz L, Mateos R, Bravo L. Regular consumption of a cocoa product improves the cardiometabolic profile in healthy and moderately hypercholesterolaemic adults. Br J Nutr. 2014;111(1):122-134. doi:10.1017/S000711451300202X | Intervention/Exposure
2049 | Sarter B, Campbell TC, Fuhrman J. Effect of a high nutrient density diet on long-term weight loss: a retrospective chart review. Altern Ther Health Med. 2008;14(3):48-53. | Intervention/Exposure
2050 | Sartika RA. Effect of trans fatty acids intake on blood lipid profile of workers in East Kalimantan, Indonesia. Malays J Nutr. 2011;17(1):119-27. | Intervention/Exposure
2051 | Sartorelli DS, Sciarra EC, Franco LJ, Cardoso MA. Beneficial effects of short-term nutritional counselling at the primary health-care level among Brazilian adults. Public Health Nutr. 2005;8(7):820-5. doi:10.1079/phn2005737 | Intervention/Exposure
2052 | Sasaki S, Ishikawa T, Yanagibori R, Amano K. Responsiveness to a self-administered diet history questionnaire in a work-site dietary intervention trial for mildly hypercholesterolemic Japanese subjects: correlation between change in dietary habits and serum cholesterol levels. J Cardiol. 1999;33(6):327-338. | Study design; Intervention/Exposure
2053 | Sathyanarayana Rao TS, Yeragani VK. Hypertensive crisis and cheese. Indian J Psychiatry. 2009;51(1):65-6. doi:10.4103/0019-5545.44910 | Study design
2054 | Sauvaget C, Nagano J, Allen N, Grant EJ, Beral V. Intake of animal products and stroke mortality in the Hiroshima/Nagasaki Life Span Study. Int J Epidemiol. 2003;32(4):53643. doi:10.1093/ije/dyg151 | Intervention/Exposure; Comparator
2055 | Sauvaget C, Nagano J, Hayashi M, Yamada M. Animal protein, animal fat, and cholesterol intakes and risk of cerebral infarction mortality in the adult health study. Stroke. Jul 2004;35(7):1531-7. doi:10.1161/01.STR.0000130426.52064.09 | Intervention/Exposure
2056 | Sawrey-Kubicek L, Zhu CH, Stevens A, et al. Whole egg increases high density lipoprotein-cholesterol (HDL-C) levels in overweight postmenopausal women. Faseb Journal. 2017;31(1 Supplement 1). doi:10.1096/fasebj.31.1_supplement.lb285 | Study design; Intervention/Exposure
2057 | Sayer RD, Speaker KJ, Pan Z, Peters JC, Wyatt HR, Hill JO. Equivalent reductions in body weight during the Beef WISE Study: beef’s role in weight improvement, satisfaction and energy. Obes Sci Pract. 2017;3(3):298-310. doi:10.1002/osp4.118 | Intervention/Exposure
2058 | Sayer RD, Wright AJ, Chen N, Campbell WW. Dietary Approaches to Stop Hypertension diet retains effectiveness to reduce blood pressure when lean pork is substituted for chicken and fish as the predominant source of protein. Am J Clin Nutr. 2015;102(2):302-8. doi:10.3945/ajcn.115.111757 | Comparator
2059 | Sayón-Orea C, Bes-Rastrollo M, Martí A, Pimenta AM, Martín-Calvo N, Martínez-González MA. Association between yogurt consumption and the risk of metabolic syndrome over 6 years in the SUN study. BMC Public Health. 2015;15:170. doi:10.1186/s12889-015-1518-7 | Comparator
2060 | Schaafsma G, Meuling WJ, van Dokkum W, Bouley C. Effects of a milk product, fermented by Lactobacillus acidophilus and with fructo-oligosaccharides added, on blood lipids in male volunteers. Eur J Clin Nutr. 1998;52(6):436-40. doi:10.1038/sj.ejcn.1600583 | Intervention/Exposure; Duration
2061 | Schaefer EJ, Lamon-Fava S, Ausman LM, et al. Individual variability in lipoprotein cholesterol response to National Cholesterol Education Program Step 2 diets. Am J Clin Nutr. 1997;65(3):823-30. doi:10.1093/ajcn/65.3.823 | Intervention/Exposure
2062 | Schaefer EJ, Lamon-Fava S, Spiegelman D, et al. Changes in plasma lipoprotein concentrations and composition in response to a low-fat, high-fiber diet are associated with changes in serum estrogen concentrations in premenopausal women. Metabolism. 1995;44(6):749-56. doi:10.1016/0026-0495(95)90188-4 | Intervention/Exposure
2063 | Schaefer EJ, Lichtenstein AH, Lamon-Fava S, et al. Body weight and low-density lipoprotein cholesterol changes after consumption of a low-fat ad libitum diet. JAMA. 1995;274(18):1450-5. doi:10.1001/jama.1995.03530180044028 | Intervention/Exposure; Sample size/Power
2064 | Schaefer EJ, Lichtenstein AH, Lamon-Fava S, et al. Effects of National Cholesterol Education Program Step 2 diets relatively high or relatively low in fish-derived fatty acids on plasma lipoproteins in middle-aged and elderly subjects. Am J Clin Nutr. 1996;63(2):234-41. doi:10.1093/ajcn/63.2.234 | Intervention/Exposure; Sample size/Power
2065 | Schaefer EJ, Lichtenstein AH, Lamon-Fava S, et al. Efficacy of a National Cholesterol Education Program Step 2 diet in normolipidemic and hypercholesterolemic middle-aged and elderly men and women. Arterioscler Thromb Vasc Biol. 1995;15(8):1079-85. doi:10.1161/01.atv.15.8.1079 | Intervention/Exposure; Sample size/Power
2066 | Schmedes M, Balderas C, Aadland EK, et al. The Effect of Lean-Seafood and Non-Seafood Diets on Fasting and Postprandial Serum Metabolites and Lipid Species: Results from a Randomized Crossover Intervention Study in Healthy Adults. Nutrients. 2018;10(5)doi:10.3390/nu10050598 | Intervention/Exposure; Sample size/Power
2067 | Schmid D, Song M, Zhang X, et al. Yogurt consumption in relation to mortality from cardiovascular disease, cancer, and all causes: a prospective investigation in 2 cohorts of US women and men. Am J Clin Nutr. 2020;111(3):689-697. doi:10.1093/ajcn/nqz345 | Outcome
2068 | Schmidt KA, Cromer G, Burhans MS, et al. Impact of low-fat and full-fat dairy foods on fasting lipid profile and blood pressure: exploratory endpoints of a randomized controlled trial. Am J Clin Nutr. 2021;114(3):882-892. doi:10.1093/ajcn/nqab131 | Sample size/Power
2069 | Schmidt KA, Cromer G, Burhans MS, et al. The impact of diets rich in low-fat or full-fat dairy on glucose tolerance and its determinants: a randomized controlled trial. Am J Clin Nutr. 2021;113(3):534-547. doi:10.1093/ajcn/nqaa301 | Outcome; Sample size/Power
2070 | Schoenaker DA, Soedamah-Muthu SS, Callaway LK, Mishra GD. Prepregnancy dietary patterns and risk of developing hypertensive disorders of pregnancy: results from the Australian Longitudinal Study on Women’s Health. Am J Clin Nutr. 2015;102(1):94-101. doi:10.3945/ajcn.114.102475 | Intervention/Exposure; Outcome
2071 | Scholtz SC, Pieters M, Oosthuizen W, Jerling JC, Bosman MJ, Vorster HH. The effect of red palm olein and refined palm olein on lipids and haemostatic factors in hyperfibrinogenaemic subjects. Thromb Res. 2004;113(1):13-25. doi:10.1016/j.thromres.2004.02.004 | Sample size/Power
2072 | Schooling CM, Kwok MK, Zhao JV. The relationship of fatty acids to ischaemic heart disease and lifespan in men and women using Mendelian randomization. Int J Epidemiol. 2023;52(6):1845-1852. doi:10.1093/ije/dyad108 | Intervention/Exposure
2073 | Schulze MB, Hoffmann K, Kroke A, Boeing H. Risk of hypertension among women in the EPIC-Potsdam Study: comparison of relative risk estimates for exploratory and hypothesis-oriented dietary patterns. Am J Epidemiol. 2003;158(4):365-73. doi:10.1093/aje/kwg156 | Intervention/Exposure
2074 | Schwab U, Uusitupa M, Karhapaa P, et al. Effects of two fat-modified diets on glucose and lipid metabolism in healthy subjects. Ann N Y Acad Sci. 1993;683:279-80. doi:10.1111/j.1749-6632.1993.tb35717.x | Intervention/Exposure; Sample size/Power
2075 | Schwab US, Agren JJ, Valve R, et al. The impact of the leucine 7 to proline 7 polymorphism of the neuropeptide Y gene on postprandial lipemia and on the response of serum total and lipoprotein lipids to a reduced fat diet. Eur J Clin Nutr. 2002;56(2):149-56. doi:10.1038/sj.ejcn.1601297 | Duration; Sample size/Power
2076 | Schwab US, Ausman LM, Vogel S, et al. Dietary cholesterol increases the susceptibility of low density lipoprotein to oxidative modification. Atherosclerosis. 2000;149(1):83-90. doi:10.1016/s0021-9150(99)00310-x | Sample size/Power
2077 | Schwab US, Maliranta HM, Sarkkinen ES, Savolainen MJ, Kesaniemi YA, Uusitupa MI. Different effects of palmitic and stearic acid-enriched diets on serum lipids and lipoproteins and plasma cholesteryl ester transfer protein activity in healthy young women. Metabolism. 1996;45(2):143-9. doi:10.1016/s0026-0495(96)90044-x | Sample size/Power
2078 | Schwab US, Niskanen LK, Maliranta HM, Savolainen MJ, Kesaniemi YA, Uusitupa MIJ. Lauric and palmitic acid-enriched diets have minimal impact on serum-lipid and lipoprotein concentrations and glucose-metabolism in healthy-young women. J Nutr. 1995;125(3):466-473. doi:10.1093/jn/125.3.466 | Intervention/Exposure; Sample size/Power
2079 | Schwab US, Vogel S, Lammi-Keefe CJ, et al. Varying dietary fat type of reduced-fat diets has little effect on the susceptibility of LDL to oxidative modification in moderately hypercholesterolemic subjects. J Nutr. 1998;128(10):1703-1709. doi:10.1093/jn/128.10.1703 | Sample size/Power
2080 | Schwandt P, Bertsch T, Haas GM. Sustained lifestyle advice and cardiovascular risk factors in 687 biological child-parent pairs: the PEP Family Heart Study. Atherosclerosis. 2011;219(2):937-45. doi:10.1016/j.atherosclerosis.2011.09.032 | Intervention/Exposure
2081 | Schwandt P, Haas GM, Bertsch T. Nutrition and cardiovascular risk factors in four age groups of female individuals: The PEP Family Heart Study. Int J Prev Med. 2010;1(2):103-9. | Study design
2082 | Schwartz BH, Choi SY, Mathews A, et al. Dietary Composition, Angiographic Coronary Disease, and Cardiovascular Outcomes in the WISE Study (Women’s Ischemia Syndrome Evaluation). J Clin Med. 2023;12(24):7762. Published 2023 Dec 18. doi:10.3390/jcm12247762 | Health status
2083 | Schwingel A, Nakata Y, Ito LS, et al. Lower HDL-cholesterol among healthy middle-aged Japanese-Brazilians in Sao Paulo compared to Natives and Japanese-Brazilians in Japan. European Journal of Epidemiology. Jan 2007;22(1):33-42. doi:10.1007/s10654-006-9093-y | Study design
2084 | Schwingshackl L, Knuppel S, Michels N, et al. Intake of 12 food groups and disability-adjusted life years from coronary heart disease, stroke, type 2 diabetes, and colorectal cancer in 16 European countries. Eur J Epidemiol. 2019;34(8):765-775. doi:10.1007/s10654-019-00523-4 | Study design
2085 | Sciarrone SE, Rouse IL, Rogers P, Beilin LJ. A factorial study of fat and fibre changes and sodium restriction on blood pressure of human hypertensive subjects. Clin Exp Pharmacol Physiol. 1990;17(3):197-201. doi:10.1111/j.1440-1681.1990.tb01305.x | Intervention/Exposure
2086 | Sciarrone SE, Strahan MT, Beilin LJ, Burke V, Rogers P, Rouse IR. Ambulatory blood pressure and heart rate responses to vegetarian meals. J Hypertens. 1993;11(3):277-85. doi:10.1097/00004872-199303000-00008 | Intervention/Exposure; Sample size/Power
2087 | Seah JYH, Ong CN, Koh WP, Yuan JM, van Dam RM. A dietary pattern derived from reduced rank regression and fatty acid biomarkers is associated with lower risk of type 2 diabetes and coronary artery disease in Chinese adults. J Nutr. 2019;149(11):2001-2010. doi:10.1093/jn/nxz164 | Intervention/Exposure
2088 | Seeba NN, Risti R, Lõokene A. Lipoprotein lipase activity does not differ in the serum environment of vegans and omnivores. Nutrients. 2023;15(12):2755. doi:10.3390/nu15122755 | Intervention/Exposure; Sample size/Power
2089 | Segawa H, Kondo K, Kadota A, et al. Association of red meat intake with the risk of cardiovascular mortality in general Japanese stratified by kidney function: NIPPON DATA80. Nutrients. 2020;12(12):1-10. doi:10.3390/nu12123707 | Comparator
2090 | Sehayek E, Nath C, Heinemann T, et al. U-shape relationship between change in dietary cholesterol absorption and plasma lipoprotein responsiveness and evidence for extreme interindividual variation in dietary cholesterol absorption in humans. J Lipid Res. 1998;39(12):2415-2422. | Intervention/Exposure; Duration; Sample size/Power
2091 | Seidel C, Deufel T, Jahreis G. Effects of fat-modified dairy products on blood lipids in humans in comparison with other fats. Ann Nutr Metab. 2005;49(1):42-8. doi:10.1159/000084176 | Duration
2092 | Seidelmann SB, Claggett B, Cheng S, et al. Dietary carbohydrate intake and mortality: a prospective cohort study and meta-analysis. Lancet Public Health. 2018;3(9):e419-e428. doi:10.1016/S2468-2667(18)30135-X | Study design; Intervention/Exposure
2093 | Seino F, Date C, Nakayama T, et al. Dietary lipids and incidence of cerebral infarction in a Japanese rural community. J Nutr Sci Vitaminol (Tokyo). 1997;43(1):83-99. doi:10.3177/jnsv.43.83 | Intervention/Exposure
2094 | Sellem L, Antoni R, Koutsos A, et al. Impact of a food-based dietary fat exchange model for replacing dietary saturated with unsaturated fatty acids in healthy men on plasma phospholipids fatty acid profiles and dietary patterns. Eur J Nutr. 2022;61(7):3669-3684. doi:10.1007/s00394-022-02910-2 | Intervention/Exposure; Outcome
2095 | Sellem L, Eichelmann F, Jackson KG, Wittenbecher C, Schulze MB, Lovegrove JA. Replacement of dietary saturated with unsaturated fatty acids is associated with beneficial effects on lipidome metabolites: a secondary analysis of a randomized trial. Am J Clin Nutr. Jun 2023;117(6):1248-1261. doi:10.1016/j.ajcnut.2023.03.024 | Intervention/Exposure
2096 | Sellem L, Srour B, Jackson KG, et al. Consumption of dairy products and cardiovascular disease risk: results from the French prospective cohort NutriNet-Santé. al article. British journal of nutrition. 2021; | Comparator
2097 | Senanayake VK, Pu S, Jenkins DA, et al. Plasma fatty acid changes following consumption of dietary oils containing n-3, n-6, and n-9 fatty acids at different proportions: preliminary findings of the Canola Oil Multicenter Intervention Trial (COMIT). Trials. 2014;15:136. doi:10.1186/1745-6215-15-136 | Intervention/Exposure; Comparator
2098 | Seppänen-Laakso T, Vanhanen H, Laakso I, Kohtamaki H, Viikari J. Replacement of butter on bread by rapeseed oil and rapeseed oil-containing margarine: effects on plasma fatty acid composition and serum cholesterol. Br J Nutr. 1992;68(3):639-54. doi:10.1079/bjn19920122 | Intervention/Exposure
2099 | Seppänen-Laakso T, Vanhanen H, Laakso I, Kohtamaki H, Viikari J. Replacement of margarine on bread by rapeseed and olive oils: effects on plasma fatty acid composition and serum cholesterol. Ann Nutr Metab. 1993;37(4):161-74. doi:10.1159/000177765 | Intervention/Exposure; Sample size/Power
2100 | Seppo L, Jauhiainen T, Poussa T, Korpela R. A fermented milk high in bioactive peptides has a blood pressure-lowering effect in hypertensive subjects. Am J Clin Nutr. 2003;77(2):326-330. doi:10.1093/ajcn/77.2.326 | Intervention/Exposure
2101 | Sessions VA, Lovegrove JA, Taylor GRJ, et al. The effect of a new fermented milk product on total plasma cholesterol, LDL-cholesterol and apolipoprotein B concentrations in middle-aged men and women. In: Functional foods: the consumer, the products and the evidence; 1998;15-19 ref 9. | Publication status
2102 | Setiono FJ, Jock B, Trude A, et al. Associations between Food Consumption Patterns and Chronic Diseases and Self-Reported Morbidities in 6 American Indian Communities. Article. Current Developments in Nutrition. 2019;3:69-80. doi:ARTN nzz06710.1093/cdn/nzz067 | Study design
2103 | Setyawati A, Sangkala MS, Malasari S, et al. Virgin Coconut Oil: A Dietary Intervention for Dyslipidaemia in Patients with Diabetes Mellitus. Nutrients. Jan 21 2023;15(3)doi:10.3390/nu15030564 | Health status
2104 | Severins N, Mensink RP, Plat J. Effects of lutein-enriched egg yolk in buttermilk or skimmed milk on serum lipids & lipoproteins of mildly hypercholesterolemic subjects. Nutr Metab Cardiovasc Dis. Feb 2015;25(2):210-7. doi:10.1016/j.numecd.2014.10.003 | Intervention/Exposure; Comparator; Sample size/Power
2105 | Seyedi SHS, Mottaghi A, Mirmiran P, Hedayati M, Azizi F. The relationship between dietary patterns and lipoprotein-associated phospholipase A2 levels in adults with cardiovascular risk factors: Tehran Lipid and Glucose Study. J Res Med Sci. 2020;25:3. Published 2020 Jan 20. doi:10.4103/jrms.JRMS_256_19 | Intervention/Exposure
2106 | Seymour JD, Calle EE, Flagg EW, Coates RJ, Ford ES, Thun MJ. Diet quality index as a predictor of short-term mortality in the American Cancer Society Cancer Prevention Study II Nutrition Cohort. Article. American Journal of Epidemiology. Jun 1 2003;157(11):980-988. doi:10.1093/aje/kwg077 | Intervention/Exposure
2107 | Shah NS, Leonard D, Finley CE, et al. Dietary Patterns and Long-Term Survival: A Retrospective Study of Healthy Primary Care Patients. Article. Am J Med. Jan 2018;131(1):48-55. doi:10.1016/j.amjmed.2017.08.010 | Comparator
2108 | Shah R, Makarem N, Emin M, Liao M, Jelic S, Aggarwal B. Mediterranean diet components are linked to greater endothelial function and lower inflammation in a pilot study of ethnically diverse women. Nutr Res. Mar 2020;75:77-84. doi:10.1016/j.nutres.2020.01.004 | Outcome
2109 | Shah RV, Steffen LM, Nayor M, et al. Dietary metabolic signatures and cardiometabolic risk. Eur Heart J. Feb 14 2023;44(7):557-569. doi:10.1093/eurheartj/ehac446 | Intervention/Exposure
2110 | Shah S, MacDonald CJ, El Fatouhi D, et al. The associations of the Palaeolithic diet alone and in combination with lifestyle factors with type 2 diabetes and hypertension risks in women in the E3N prospective cohort. Eur J Nutr. Oct 2021;60(7):3935-3945. doi:10.1007/s00394-021-02565-5 | Intervention/Exposure
2111 | Shahar DR, Abel R, Elhayany A, Vardi H, Fraser D. Does dairy calcium intake enhance weight loss among overweight diabetic patients? Shahar, DR, Abel, R, Elhayany, A, et al. Does dairy calcium intake enhance weight loss among overweight diabetic patients?. Diabetes Care. 2007;30(3):485-489. doi:10.2337/dc06-1564 | Intervention/Exposure; Health status
2112 | Shahar DR, Froom P, Harari G, Yerushalmi N, Lubin F, Kristal-Boneh E. Changes in dietary intake account for seasonal changes in cardiovascular disease risk factors. Eur J Clin Nutr. May 1999;53(5):395-400. doi:10.1038/sj.ejcn.1600761 | Intervention/Exposure
2113 | Shai I, Schwarzfuchs D, Henkin Y, et al. Weight loss with a low-carbohydrate, Mediterranean, or low-fat diet. N Engl J Med. Jul 17 2008;359(3):229-41. doi:10.1056/NEJMoa0708681 | Intervention/Exposure
2114 | Shakiba E, Najafi F, Pasdar Y, et al. A prospective cohort study on the association between dietary fatty acids intake and risk of hypertension incident. Sci Rep. 2023;13(1):21112. Published 2023 Nov 30. doi:10.1038/s41598-023-48256-5 | Intervention/Exposure
2115 | Shams-White MM, Brockton NT, Mitrou P, Kahle LL, Reedy J. The 2018 World Cancer Research Fund/American Institute for Cancer Research (WCRF/AICR) Score and All-Cause, Cancer, and Cardiovascular Disease Mortality Risk: A Longitudinal Analysis in the NIH-AARP Diet and Health Study. Article. Curr Dev Nutr. Jun 2022;6(6):nzac096. doi:10.1093/cdn/nzac096 | Comparator
2116 | Shang X, Li Y, Liu A, et al. Dietary pattern and its association with the prevalence of obesity and related cardiometabolic risk factors among Chinese children. PLoS One. 2012;7(8):e43183. doi:10.1371/journal.pone.0043183 | Intervention/Exposure; Country
2117 | Shang X, Li Y, Xu H, et al. Leading dietary determinants identified using machine learning techniques and a healthy diet score for changes in cardiometabolic risk factors in children: a longitudinal analysis. Nutr J. Sep 19 2020;19(1):105. doi:10.1186/s12937-020-00611-2 | Intervention/Exposure; Outcome; Country
2118 | Shang X, Scott D, Hodge A, et al. Dietary protein from different food sources, incident metabolic syndrome and changes in its components: An 11-year longitudinal study in healthy community-dwelling adults. Clin Nutr. Dec 2017;36(6):1540-1548. doi:10.1016/j.clnu.2016.09.024 | Intervention/Exposure
2119 | Shankar SR, Bijlani RL, Baveja T, et al. Effect of partial replacement of visible fat by ghee (clarified butter) on serum lipid profile. Indian J Physiol Pharmacol. Jul 2002;46(3):355-60. | Country; Sample size/Power
2120 | Shannon BM, Tershakovec AM, Martel JK, et al. Reduction of Elevated Ldl-Cholesterol Levels of 4-Year-Old to 10-Year-Old Children through Home-Based Dietary Education. Pediatrics. Dec 1994;94(6):923-927. | Intervention/Exposure
2121 | Sharifan P, Ziaee A, Darroudi S, et al. Effect of low-fat dairy products fortified with 1500IU nano encapsulated vitamin D(3) on cardiometabolic indicators in adults with abdominal obesity: a total blinded randomized controlled trial. Journal article. Curr Med Res Opin. Apr 2021;37(4):579-588. doi:10.1080/03007995.2021.1874324 | Comparator
2122 | Sharlin J, Posner BM, Gershoff SN, Zeitlin MF, Berger PD. Nutrition and behavioral characteristics and determinants of plasma cholesterol levels in men and women. J Am Diet Assoc. Apr 1992;92(4):434-40. | Study design; Intervention/Exposure
2123 | Sharma S, Cruickshank JK, Green DM, Vik S, Tome A, Kolonel LN. Impact of diet on mortality from stroke: results from the U.S. multiethnic cohort study. J Am Coll Nutr. 2013;32(3):151-9. doi:10.1080/07315724.2013.791798 | Comparator
2124 | Sharman MJ, Gómez AL, Kraemer WJ, Volek JS. Very Low-Carbohydrate and Low-Fat Diets Affect Fasting Lipids and Postprandial Lipemia Differently in Overweight Men. Article. Journal of Nutrition. 2004;134(4):880-885. | Sample size/Power
2125 | Sharman MJ, Kraemer WJ, Love DM, et al. A ketogenic diet favorably affects serum biomarkers for cardiovascular disease in normal-weight men. J Nutr. Jul 2002;132(7):1879-85. doi:10.1093/jn/132.7.1879 | Intervention/Exposure; Sample size/Power
2126 | Sharpe SJ, Gamble GD, Sharpe DN. Cholesterol-lowering and blood pressure effects of immune milk. Am J Clin Nutr. Apr 1994;59(4):929-34. doi:10.1093/ajcn/59.4.929 | Intervention/Exposure; Sample size/Power
2127 | Shatwan IM, Weech M, Jackson KG, Lovegrove JA, Vimaleswaran KS. Apolipoprotein E gene polymorphism modifies fasting total cholesterol concentrations in response to replacement of dietary saturated with monounsaturated fatty acids in adults at moderate cardiovascular disease risk. Lipids Health Dis. Nov 23 2017;16(1):222. doi:10.1186/s12944-017-0606-3 | Intervention/Exposure
2128 | Shay CM, Stamler J, Dyer AR, et al. Nutrient and food intakes of middle-aged adults at low risk of cardiovascular disease: the international study of macro-/micronutrients and blood pressure (INTERMAP). European Journal of Nutrition. Dec 2012;51(8):917-926. doi:10.1007/s00394-011-0268-2 | Study design; Intervention/Exposure
2129 | Shea S, Basch CE, Irigoyen M, et al. Relationships of dietary fat consumption to serum total and low-density lipoprotein cholesterol in hispanic preschool children. Prev Med. Mar 1991;20(2):237-49. doi:10.1016/0091-7435(91)90023-w | Intervention/Exposure
2130 | Shea S, Basch CE, Irigoyen M, Zybert P, Contento I, Gutin B. Relationships between Diet and Blood Lipid-Levels in Hispanic Preschool-Children. Annals of the New York Academy of Sciences. Apr 12 1991;623:462-463. doi:DOI 10.1111/j.1749-6632.1991.tb43772.x | Intervention/Exposure
2131 | Shea S, Melnik TA, Stein AD, Zansky SM, Maylahn C, Basch CE. Age, sex, educational attainment, and race/ethnicity in relation to consumption of specific foods contributing to the atherogenic potential of diet. Prev Med. Mar 1993;22(2):203-18. doi:10.1006/pmed.1993.1017 | Study design; Comparator
2132 | Sheehy S, Palmer JR, Rosenberg L. High Consumption of Red Meat Is Associated with Excess Mortality Among African-American Women. J Nutr. Dec 10 2020;150(12):3249-3258. doi:10.1093/jn/nxaa282 | Outcome; Comparator
2133 | Shemirani F, Djafarian K, Fotouhi A, et al. Effect of Paleolithic-based low-carbohydrate vs. moderate-carbohydrate diets with portion-control and calorie-counting on CTRP6, asprosin and metabolic markers in adults with metabolic syndrome: A randomized clinical trial. Clin Nutr ESPEN. Apr 2022;48:87-98. doi:10.1016/j.clnesp.2021.11.013 | Intervention/Exposure
2134 | Shi J, Fang HY, Cheng X, et al. Nutrient Patterns and Its Association and Metabolic Syndrome among Chinese Children and Adolescents Aged 7-17. Nutrients. Jan 2023;15(1)doi:ARTN 117 10.3390/nu15010117 | Intervention/Exposure
2135 | Shi Z, Ganji V. Dietary patterns and cardiovascular disease risk among Chinese adults: a prospective cohort study. Eur J Clin Nutr. Dec 2020;74(12):1725-1735. doi:10.1038/s41430-020-0668-6 | Intervention/Exposure; Country
2136 | Shi Z, Papier K, Yiengprugsawan V, Kelly M, Seubsman SA, Sleigh AC. Dietary patterns associated with hypertension risk among adults in Thailand: 8-year findings from the Thai Cohort Study. Public Health Nutr. Feb 2019;22(2):307-313. doi:10.1017/S1368980018002203 | Intervention/Exposure
2137 | Shiina Y, Funabashi N, Lee K, et al. Acute effect of oral flavonoid-rich dark chocolate intake on coronary circulation, as compared with non-flavonoid white chocolate, by transthoracic Doppler echocardiography in healthy adults. International Journal of Cardiology. Jan 24 2009;131(3):424-429. doi:10.1016/j.ijcard.2007.07.131 | Duration; Comparator; Sample size/Power
2138 | Shikany JM, Jacobs DR, Jr., Lewis CE, et al. Associations between food groups, dietary patterns, and cardiorespiratory fitness in the Coronary Artery Risk Development in Young Adults study. Am J Clin Nutr. Dec 2013;98(6):1402-9. doi:10.3945/ajcn.113.058826 | Study design
2139 | Shikany JM, Safford MM, Newby PK, Durant RW, Brown TM, Judd SE. Southern Dietary Pattern is Associated With Hazard of Acute Coronary Heart Disease in the Reasons for Geographic and Racial Differences in Stroke (REGARDS) Study. Circulation. Sep 1 2015;132(9):804-14. doi:10.1161/CIRCULATIONAHA.114.014421 | Intervention/Exposure
2140 | Shimazu T, Kuriyama S, Hozawa A, et al. Dietary patterns and cardiovascular disease mortality in Japan: a prospective cohort study. Int J Epidemiol. Jun 2007;36(3):600-9. doi:10.1093/ije/dym005 | Intervention/Exposure
2141 | Shin H, Yoon YS, Lee Y, Kim CI, Oh SW. Dairy product intake is inversely associated with metabolic syndrome in Korean adults: Anseong and Ansan cohort of the Korean Genome and Epidemiology Study. J Korean Med Sci. Oct 2013;28(10):1482-8. doi:10.3346/jkms.2013.28.10.1482 | Intervention/Exposure; Comparator
2142 | Shin JY, Kim JM, Kim Y. Associations between dietary patterns and hypertension among Korean adults: the Korean National Health and Nutrition Examination Survey (2008-2010). Nutr Res Pract. Jun 2013;7(3):224-32. doi:10.4162/nrp.2013.7.3.224 | Intervention/Exposure
2143 | Shin MJ, Rim SJ, Jang YS, et al. The cholesterol-lowering effect of plant sterol-containing beverage in hypercholesterolemic subjects with low cholesterol intake. Nutrition Research. Apr 2003;23(4):489-496. doi:10.1016/S0271-5317(03)00016-2 | Intervention/Exposure; Comparator
2144 | Shlisky JD, Durward CM, Zack MK, Gugger CK, Campbell JK, Nickols-Richardson SM. An energy-reduced dietary pattern, including moderate protein and increased nonfat dairy intake combined with walking promotes beneficial body composition and metabolic changes in women with excess adiposity: a randomized comparative trial. Food Sci Nutr. Sep 2015;3(5):376-93. doi:10.1002/fsn3.231 | Intervention/Exposure; Comparator
2145 | Si J, Chen L, Yu C, et al. Healthy lifestyle, DNA methylation age acceleration, and incident risk of coronary heart disease. Clin Epigenetics. Mar 28 2023;15(1):52. doi:10.1186/s13148-023-01464-2 | Country
2146 | Sichieri R, Moura AS, Genelhu V, Hu F, Willett WC. An 18-mo randomized trial of a low-glycemic-index diet and weight change in Brazilian women. Am J Clin Nutr. Sep 2007;86(3):707-13. doi:10.1093/ajcn/86.3.707 | Intervention/Exposure
2147 | Sidossis LS, Mittendorfer B. Effects of diet composition on triacylglycerol metabolism in humans. Clin Nutr. Apr 1999;18(2):107-9. doi:10.1054/clnu.1998.0016 | Intervention/Exposure; Publication status
2148 | Silva FM, Giatti L, Diniz M, Brant LCC, Barreto SM. Dairy product consumption reduces cardiovascular mortality: results after 8 year follow-up of ELSA-Brasil. Eur J Nutr. Mar 2022;61(2):859-869. doi:10.1007/s00394-021-02686-x | Comparator
2149 | Silva KD, Kelly CN, Jones AE, et al. Chylomicron particle size and number, factor VII activation and dietary monounsaturated fatty acids. Atherosclerosis. Jan 2003;166(1):73-84. doi:10.1016/s0021-9150(02)00306-4 | Study design; Intervention/Exposure
2150 | Silva KF, Prata A, Cunha DF. Frequency of metabolic syndrome and the food intake patterns in adults living in a rural area of Brazil. Article. Rev Soc Bras Med Trop. Jul-Aug 2011;44(4):425-9. doi:10.1590/s0037-86822011000400005 | Study design
2151 | Simão AN, Lozovoy MA, Bahls LD, et al. Blood pressure decrease with ingestion of a soya product (kinako) or fish oil in women with the metabolic syndrome: role of adiponectin and nitric oxide. Br J Nutr. Oct 28 2012;108(8):1435-42. doi:10.1017/S0007114511006921 | Intervention/Exposure
2152 | Simell O, Niinikoski H, Viikari J, Rask-Nissila L, Tammi A, Ronnemaa T. Cardiovascular disease risk factors in young children in the STRIP baby project. Special Turku coronary Risk factor Intervention Project for children. Ann Med. Apr 1999;31 Suppl 1:55-61. | Intervention/Exposure
2153 | Simkin-Silverman L, Wing RR, Hansen DH, et al. Prevention of cardiovascular risk factor elevations in healthy premenopausal women. Prev Med. Sep 1995;24(5):509-17. doi:10.1006/pmed.1995.1081 | Intervention/Exposure
2154 | Simonen P, Arte E, Gylling H. Obesity does not interfere with the cholesterol-lowering effect of plant stanol ester consumption (As part of a heart-healthy diet). Article. Journal of Cardiovascular Development and Disease. 2021;8(4) | Intervention/Exposure; Health status; Comparator; Sample size/Power
2155 | Simons LA. Additive effect of plant sterol-ester margarine and cerivastatin in lowering low-density lipoprotein cholesterol in primary hypercholesterolemia. Am J Cardiol. Oct 1 2002;90(7):737-40. doi:10.1016/s0002-9149(02)02600-0 | Intervention/Exposure; Comparator
2156 | Simpson EJ, Clark M, Razak AA, Salter A. The impact of reduced red and processed meat consumption on cardiovascular risk factors; an intervention trial in healthy volunteers. Food Funct. Oct 16 2019;10(10):6690-6698. doi:10.1039/c9fo00758j | Study design; Intervention/Exposure
2157 | Sinclair AJ, Johnson L, O’Dea K, Holman RT. Diets rich in lean beef increase arachidonic acid and long-chain omega 3 polyunsaturated fatty acid levels in plasma phospholipids. Lipids. May 1994;29(5):337-43. doi:10.1007/BF02537187 | Study design; Outcome
2158 | Singh RB, Fedacko J, Vargova V, Pella D, Niaz MA, Ghosh S. Effect of low W-6/W-3 fatty acid ratio Paleolithic style diet in patients with acute coronary syndromes: a randomized, single blind, controlled trial. | Health status
2159 | Singh RB, Sharma VK, Gupta RK, Singh R. Nutritional modulators of lipoprotein metabolism in patients with risk factors for coronary heart disease: diet and moderate exercise trial. J Am Coll Nutr. Aug 1992;11(4):391-8. doi:10.1080/07315724.1992.10718242 | Intervention/Exposure; Country
2160 | Singh RB, Sharma VK, Rastogi SS, Singh NK. In patients with mild hypertension, does exercise and a gradual rather than abrupt increase in fatty acid and salt intake cause less rise in cardiovascular risk factors? Clin Nutr. 1992;11(5):309-314. doi:10.1016/0261-5614(92)90009-f | Country; Sample size/Power
2161 | Singh RB, Singh NK, Rastogi SS, Mani UV, Niaz MA. Effects of diet and lifestyle changes on atherosclerotic risk factors after 24 weeks on the Indian Diet Heart Study. Am J Cardiol. Jun 1 1993;71(15):1283-8. doi:10.1016/0002-9149(93)90541-j | Intervention/Exposure; Country
2162 | Singh RB, Sircar AR, Singh RG, Mani UV, Seth J, Devi L. Dietary modulators of lipid metabolism in the Indian diet-heart study (I.D.H.S.). Int J Vitam Nutr Res. 1992;62(1):73-82. | Country
2163 | Singh, RB, Rastogi, SS, Singh, R, et al. Effects on plasma ascorbic acid and coronary risk factors of adding guava fruit to the usual diet in hypertensives with mild to moderate hypercholesterolaemia. Journal of Nutritional & Environmental Medicine. 1997. doi:10.1080/13590849762754; Singh RB, Rastogi SS, Singh R, Niaz MA, Singh NK, Madhu SV. Effects on plasma ascorbic acid and coronary risk factors of adding guava fruit to the usual diet in hypertensives with mild to moderate hypercholesterolaemia. | Intervention/Exposure; Health status; Country
2164 | Sinha R, Cross AJ, Graubard BI, Leitzmann MF, Schatzkin A. Meat intake and mortality: a prospective study of over half a million people. Arch Intern Med. Mar 23 2009;169(6):562-71. doi:10.1001/archinternmed.2009.6 | Comparator
2165 | Siren R, Eriksson JG, Peltonen M, Vanhanen H. Impact of health counselling on cardiovascular disease risk in middle aged men: influence of socioeconomic status. Article. PLoS One. 2014;9(2):e88959. doi:10.1371/journal.pone.0088959 | Intervention/Exposure
2166 | Sirtori CR, Gatti E, Tremoli E, et al. Olive oil, corn oil, and n-3 fatty acids differently affect lipids, lipoproteins, platelets, and superoxide formation in type II hypercholesterolemia. Am J Clin Nutr. Jul 1992;56(1):113-22. doi:10.1093/ajcn/56.1.113 | Intervention/Exposure; Health status
2167 | Sirtori CR, Pazzucconi F, Colombo L, Battistin P, Bondioli A, Descheemaeker K. Double-blind study of the addition of high-protein soya milk v. cows’ milk to the diet of patients with severe hypercholesterolaemia and resistance to or intolerance of statins. Br J Nutr. Aug 1999;82(2):91-6. | Sample size/Power
2168 | Skeaff CM, Thoma C, Mann J, Chisholm A, Williams S, Richmond K. Isocaloric substitution of plant sterol-enriched fat spread for carbohydrate-rich foods in a low-fat, fibre-rich diet decreases plasma low-density lipoprotein cholesterol and increases high-density lipoprotein concentrations. Nutr Metab Cardiovasc Dis. Oct 2005;15(5):337-44. doi:10.1016/j.numecd.2005.03.002 | Intervention/Exposure; Duration; Sample size/Power
2169 | Skeaff CM, Williscroft K, Mann J, Chisholm A. Replacing cows’ with sheep’s dairy fat lowers plasma cholesterol concentration in participants consuming dairy fat-rich diets. Eur J Clin Nutr. Feb 2004;58(2):250-7. doi:10.1038/sj.ejcn.1601774 | Duration
2170 | Skelly LE, Barbour-Tuck EN, Kurgan N, et al. Neutral Effect of Increased Dairy Product Intake, as Part of a Lifestyle Modification Program, on Cardiometabolic Health in Adolescent Girls With Overweight/Obesity: A Secondary Analysis From a Randomized Controlled Trial. Front Nutr. 2021;8:673589. doi:10.3389/fnut.2021.673589 | Sample size/Power
2171 | Skórkowska- Telichowska K, Kosinska J, Chwojnicka M, et al. Positive effects of egg-derived phospholipids in patients with metabolic syndrome. Adv Med Sci. Mar 2016;61(1):169-74. doi:10.1016/j.advms.2015.12.003 | Intervention/Exposure; Sample size/Power
2172 | Skov AR, Toubro S, Ronn B, Holm L, Astrup A. Randomized trial on protein vs carbohydrate in ad libitum fat reduced diet for the treatment of obesity. Int J Obes Relat Metab Disord. May 1999;23(5):528-36. doi:10.1038/sj.ijo.0800867 | Intervention/Exposure; Sample size/Power
2173 | Skrypnik K, Bogdanski P, Kubasik M, Wawrzyniak N, Markuszewski L, Suliburska J. The influence of dietary patterns on arterial stiffness, lipid metabolism, and liver and renal function in the population of Greater Poland. Acta Sci Pol Technol Aliment. Jul-Sep 2020;19(3):301-318. doi:10.17306/J.AFS.0848 | Study design; Intervention/Exposure
2174 | Slurink IA, Corpeleijn E, Bakker SJ, et al. Dairy consumption and incident prediabetes: prospective associations and network models in the large population-based Lifelines Study. Article. Am J Clin Nutr. Dec 2023;118(6):1077-1090. doi:10.1016/j.ajcnut.2023.10.002 | Outcome
2175 | Smedman AEM, Gustafsson IB, Berglund LGT, Vessby BOH. Pentadecanoic acid in serum as a marker for intake of milk fat: relations between intake of milk fat and metabolic risk factors. American Journal of Clinical Nutrition. Jan 1999;69(1):22-29. | Study design; No confounder adjustment
2176 | Smiljanec K, Mbakwe AU, Ramos-Gonzalez M, Mesbah C, Lennon SL. Associations of Ultra-Processed and Unprocessed/Minimally Processed Food Consumption with Peripheral and Central Hemodynamics, and Arterial Stiffness in Young Healthy Adults. Nutrients. Oct 22 2020;12(11)doi:10.3390/nu12113229 | Study design; Intervention/Exposure
2177 | Smith DR, Wood R, Tseng S, Smith SB. Increased beef consumption increases apolipoprotein A-I but not serum cholesterol of mildly hypercholesterolemic men with different levels of habitual beef intake. Exp Biol Med (Maywood). Apr 2002;227(4):266-75. doi:10.1177/153537020222700407 | Sample size/Power
2178 | Smith RD, Kelly CN, Fielding BA, et al. Long-term monounsaturated fatty acid diets reduce platelet aggregation in healthy young subjects. Br J Nutr. Sep 2003;90(3):597-606. doi:10.1079/bjn2003953 | Intervention/Exposure
2179 | Smith-Ryan AE, Hirsch KR, Blue MNM, Mock MG, Trexler ET. High-Fat Breakfast Meal Replacement in Overweight and Obesity: Implications on Body Composition, Metabolic Markers, and Satiety. Nutrients. Apr 17 2019;11(4)doi:10.3390/nu11040865 | Duration; Sample size/Power
2180 | Snetselaar L, Stumbo P, Chenard C, Ahrens L, Smith K, Zimmerman B. Adolescents eating diets rich in either lean beef or lean poultry and fish reduced fat and saturated fat intake and those eating beef maintained serum ferritin status. J Am Diet Assoc. Mar 2004;104(3):424-8. doi:10.1016/j.jada.2003.12.016 | Comparator
2181 | Snijder MB, van Dam RM, Stehouwer CD, Hiddink GJ, Heine RJ, Dekker JM. A prospective study of dairy consumption in relation to changes in metabolic risk factors: the Hoorn Study. Obesity (Silver Spring). Mar 2008;16(3):706-9. doi:10.1038/oby.2007.93 | Intervention/Exposure; Comparator
2182 | Snook JT, Park S, Wardlaw G, et al. Chylomicron fatty acid composition and serum lipid concentrations in subjects fed caprenin or palm oil/palm kernel oil as the major dietary fat. | Intervention/Exposure; Sample size/Power
2183 | Snook JT, Park S, Williams G, Tsai YH, Lee N. Effect of synthetic triglycerides of myristic, palmitic, and stearic acid on serum lipoprotein metabolism. Eur J Clin Nutr. Aug 1999;53(8):597-605. doi:10.1038/sj.ejcn.1600815 | Intervention/Exposure; Sample size/Power
2184 | Södergren E, Gustafsson IB, Basu S, et al. A diet containing rapeseed oil-based fats does not increase lipid peroxidation in humans when compared to a diet rich in saturated fatty acids. Eur J Clin Nutr. 2001;55(11):922-931. doi:10.1038/sj.ejcn.1601246 | Sample size/Power
2185 | Soedamah-Muthu SS, Masset G, Verberne L, Geleijnse JM, Brunner EJ. Consumption of dairy products and associations with incident diabetes, CHD and mortality in the Whitehall II study. Br J Nutr. Feb 28 2013;109(4):718-26. doi:10.1017/S0007114512001845 | Comparator
2186 | Soerensen KV, Thorning TK, Astrup A, Kristensen M, Lorenzen JK. Effect of dairy calcium from cheese and milk on fecal fat excretion, blood lipids, and appetite in young men. Am J Clin Nutr. May 2014;99(5):984-91. doi:10.3945/ajcn.113.077735 | Duration; Sample size/Power
2187 | Sofi F, Buccioni A, Cesari F, et al. Effects of a dairy product (pecorino cheese) naturally rich in cis-9, trans-11 conjugated linoleic acid on lipid, inflammatory and haemorheological variables: a dietary intervention study. Nutr Metab Cardiovasc Dis. Feb 2010;20(2):117-24. doi:10.1016/j.numecd.2009.03.004 | Sample size/Power
2188 | Solà R, Valls RM, Godas G, et al. Cocoa, hazelnuts, sterols and soluble fiber cream reduces lipids and inflammation biomarkers in hypertensive patients: a randomized controlled trial. Journal article. PLoS One. 2012;7(2):e31103. doi:10.1371/journal.pone.0031103 | Intervention/Exposure; Comparator
2189 | Somerset SM, Graham L, Markwell K. Isoenergetic replacement of dietary saturated with monounsaturated fat via macadamia nuts enhances endothelial function in overweight subjects. e-SPEN Journal. 2013. 8:e113-119. doi:10.1016/j.clnme.2013.02.003 | Intervention/Exposure
2190 | Son J, Lee Y, Park K. Effects of processed red meat consumption on the risk of type 2 diabetes and cardiovascular diseases among Korean adults: the Korean Genome and Epidemiology Study. European Journal of Nutrition. Sep 2019;58(6):2477-2484. doi:10.1007/s00394-018-1799-6 | Comparator
2191 | Sonestedt E, Borne Y, Wirfalt E, Ericson U. Dairy Consumption, Lactase Persistence, and Mortality Risk in a Cohort From Southern Sweden. Front Nutr. 2021;8:779034. doi:10.3389/fnut.2021.779034 | Outcome
2192 | Sonestedt E, Hellstrand S, Drake I, et al. Diet Quality and Change in Blood Lipids during 16 Years of Follow-up and Their Interaction with Genetic Risk for Dyslipidemia. Nutrients. May 9 2016;8(5)doi:10.3390/nu8050274 | Intervention/Exposure
2193 | Sonestedt E, Wirfalt E, Wallstrom P, Gullberg B, Orho-Melander M, Hedblad B. Dairy products and its association with incidence of cardiovascular disease: the Malmo diet and cancer cohort. Eur J Epidemiol. Aug 2011;26(8):609-18. doi:10.1007/s10654-011-9589-y | Comparator
2194 | Song J, Pan C, Li F, et al. Association between dairy consumption and ischemic heart disease among Chinese adults: a prospective study in Qingdao. Nutr Metab (Lond). Feb 19 2022;19(1):11. doi:10.1186/s12986-022-00645-9 | Country
2195 | Song M, Fung TT, Hu FB, et al. Association of Animal and Plant Protein Intake With All-Cause and Cause-Specific Mortality. JAMA Intern Med. Oct 1 2016;176(10):1453-1463. doi:10.1001/jamainternmed.2016.4182 | Intervention/Exposure
2196 | Song S, Kim J, Kim J. Gender Differences in the Association between Dietary Pattern and the Incidence of Hypertension in Middle-Aged and Older Adults. Article. Nutrients. Feb 2018;10(2)doi:ARTN 252 10.3390/nu10020252 | Intervention/Exposure
2197 | Song S, Lee JE. Dietary Patterns Related to Triglyceride and High-Density Lipoprotein Cholesterol and the Incidence of Type 2 Diabetes in Korean Men and Women. Nutrients. Dec 20 2018;11(1)doi:10.3390/nu11010008 | Intervention/Exposure
2198 | Sonnenberg LM, Quatromoni PA, Gagnon DR, et al. Diet and plasma lipids in women. II. Macronutrients and plasma triglycerides, high-density lipoprotein, and the ratio of total to high-density lipoprotein cholesterol in women: the Framingham nutrition studies. J Clin Epidemiol. Jun 1996;49(6):665-72. doi:10.1016/0895-4356(96)00031-5 | Intervention/Exposure
2199 | Sørensen NS, Marckmann P, Hoy CE, van Duyvenvoorde W, Princen HM. Effect of fish-oil-enriched margarine on plasma lipids, low-density-lipoprotein particle composition, size, and susceptibility to oxidation. Am J Clin Nutr. Aug 1998;68(2):235-41. doi:10.1093/ajcn/68.2.235 | Intervention/Exposure
2200 | Sotos-Prieto M, Mattei J, Cook NR, et al. Association Between a 20-Year Cardiovascular Disease Risk Score Based on Modifiable Lifestyles and Total and Cause-Specific Mortality Among US Men and Women. J Am Heart Assoc. Nov 6 2018;7(21):e010052. doi:10.1161/JAHA.118.010052 | Intervention/Exposure
2201 | Sotos-Prieto M. The Healthy Heart Score, a potential primordial prevention tool for cardiovascular prevention. | Study design
2202 | Spence JD, Srichaikul KK, Jenkins DJA. Cardiovascular Harm From Egg Yolk and Meat: More Than Just Cholesterol and Saturated Fat. J Am Heart Assoc. Apr 6 2021;10(7):e017066. doi:10.1161/JAHA.120.017066 | Study design
2203 | Spiller GA, Jenkins DAJ, Bosello O, Gates JE, Cragen LN, Bruce B. Nuts and plasma lipids: An almond-based diet lowers LDL-C while preserving HDL-C. Journal of the American College of Nutrition. Jun 1998;17(3):285-290. doi:Doi 10.1080/07315724.1998.10718761 | Intervention/Exposure
2204 | Spiller GA, Jenkins DJ, Cragen LN, et al. Effect of a diet high in monounsaturated fat from almonds on plasma cholesterol and lipoproteins. J Am Coll Nutr. Apr 1992;11(2):126-30. | Intervention/Exposure
2205 | Srour B, Fezeu LK, Kesse-Guyot E, et al. Ultra-processed food intake and risk of cardiovascular disease: prospective cohort study (NutriNet-Sante). BMJ. May 29 2019;365:l1451. doi:10.1136/bmj.l1451 | Intervention/Exposure
2206 | Stalenhoef AF, Hectors M, Demacker PN. Effect of plant sterol-enriched margarine on plasma lipids and sterols in subjects heterozygous for phytosterolaemia. J Intern Med. Feb 2001;249(2):163-6. doi:10.1046/j.1365-2796.2001.00788.x | Study design; Sample size/Power
2207 | Stamler J, Briefel RR, Milas C, Grandits GA, Caggiula AW. Relation of changes in dietary lipids and weight, trial years 1-6, to changes in blood lipids in the special intervention and usual care groups in the Multiple Risk Factor Intervention Trial. Am J Clin Nutr. Jan 1997;65(1 Suppl):272S-288S. doi:10.1093/ajcn/65.1.272S | Intervention/Exposure
2208 | Stamler J, Brown IJ, Yap IK, et al. Dietary and urinary metabonomic factors possibly accounting for higher blood pressure of black compared with white Americans: results of International Collaborative Study on macro-/micronutrients and blood pressure. Hypertension. Dec 2013;62(6):1074-80. doi:10.1161/HYPERTENSIONAHA.113.01810 | Intervention/Exposure
2209 | Stamler J, Caggiula A, Grandits GA, Kjelsberg M, Cutler JA. Relationship to blood pressure of combinations of dietary macronutrients. Findings of the Multiple Risk Factor Intervention Trial (MRFIT). Circulation. Nov 15 1996;94(10):2417-23. doi:10.1161/01.cir.94.10.2417 | Intervention/Exposure
2210 | Stamler J, Caggiula A, Grandits GA. More links found between diet and blood pressure. Consultant, 1997. 37(3). | Study design; Publication status
2211 | Stampfer MJ, Hu FB, Manson JE, Rimm EB, Willett WC. Primary prevention of coronary heart disease in women through diet and lifestyle. N Engl J Med. 2000;343(1):16-22. doi:10.1056/NEJM200007063430103 | Intervention/Exposure
2212 | Stancliffe RA, Thorpe T, Zemel MB. Dairy attentuates oxidative and inflammatory stress in metabolic syndrome. Am J Clin Nutr. Aug 2011;94(2):422-30. doi:10.3945/ajcn.111.013342 | Intervention/Exposure; Comparator
2213 | Stang J, Zephier EM, Story M, et al. Dietary intakes of nutrients thought to modify cardiovascular risk from three groups of American Indians: The Strong Heart Dietary Study, Phase II. J Am Diet Assoc. Dec 2005;105(12):1895-903. doi:10.1016/j.jada.2005.09.003 | Study design; Intervention/Exposure
2214 | Stanton AV, James K, Brennan MM, et al. Omega-3 index and blood pressure responses to eating foods naturally enriched with omega-3 polyunsaturated fatty acids: a randomized controlled trial. Sci Rep. Sep 22 2020;10(1):15444. doi:10.1038/s41598-020-71801-5 | Intervention/Exposure
2215 | Starc TJ, Shea S, Cohn LC, Mosca L, Gersony WM, Deckelbaum RJ. Greater dietary intake of simple carbohydrate is associated with lower concentrations of high-density-lipoprotein cholesterol in hypercholesterolemic children. Am J Clin Nutr. Jun 1998;67(6):1147-54. doi:10.1093/ajcn/67.6.1147 | Study design; Intervention/Exposure
2216 | Stasinopoulos LC, Zhou A, Hypponen E. Association of supplemental calcium and dairy milk intake with all-cause and cause-specific mortality in the UK Biobank: a prospective cohort study. Br J Nutr. Mar 14 2020;123(5):574-582. doi:10.1017/S0007114519003076 | Comparator
2217 | Stauber A, Muller A, Rommers N, et al. Association of chocolate consumption with neurological and cardiovascular outcomes in atrial fibrillation: data from two Swiss atrial fibrillation cohort studies (Swiss-AF and BEAT-AF). Swiss Med Wkly. Aug 23 2023;153:40109. doi:10.57187/smw.2023.40109 | Intervention/Exposure; Health status
2218 | Steele MG. The effect on serum cholesterol levels of substituting milk with a soya beverage. Australian Journal of Nutrition and dietetics. 1992 Mar;49(1):24-28 | Intervention/Exposure; Publication status
2219 | Stefanick ML, Mackey S, Sheehan M, Ellsworth N, Haskell WL, Wood PD. Effects of diet and exercise in men and postmenopausal women with low levels of HDL cholesterol and high levels of LDL cholesterol. N Engl J Med. Jul 2 1998;339(1):12-20. doi:10.1056/NEJM199807023390103 | Intervention/Exposure
2220 | Steffen LM, Kroenke CH, Yu X, et al. Associations of plant food, dairy product, and meat intakes with 15-y incidence of elevated blood pressure in young black and white adults: the Coronary Artery Risk Development in Young Adults (CARDIA) Study. Am J Clin Nutr. Dec 2005;82(6):1169-77; quiz 1363-4. doi:10.1093/ajcn/82.6.1169 | Intervention/Exposure; Comparator
2221 | Steffen LM, Van Horn L, Daviglus ML, et al. A modified Mediterranean diet score is associated with a lower risk of incident metabolic syndrome over 25 years among young adults: the CARDIA (Coronary Artery Risk Development in Young Adults) study. Br J Nutr. Nov 28 2014;112(10):1654-61. doi:10.1017/S0007114514002633 | Intervention/Exposure
2222 | Stefler D, Malyutina S, Kubinova R, et al. Mediterranean diet score and total and cardiovascular mortality in Eastern Europe: the HAPIEE study. Article. Eur J Nutr. Feb 2017;56(1):421-429. doi:10.1007/s00394-015-1092-x | Comparator
2223 | Steinberg FM, Guthrie NL, Villablanca AC, Kumar K, Murray MJ. Soy protein with isoflavones has favorable effects on endothelial function that are independent of lipid and antioxidant effects in healthy postmenopausal women. American Journal of Clinical Nutrition. Jul 2003;78(1):123-130. doi:DOI 10.1093/ajcn/78.1.123 | Intervention/Exposure
2224 | Steinhaus DA, Mostofsky E, Levitan EB, et al. Chocolate intake and incidence of heart failure: Findings from the Cohort of Swedish Men. Am Heart J. Jan 2017;183:18-23. doi:10.1016/j.ahj.2016.10.002 | Intervention/Exposure; Comparator
2225 | Steinmetz KA, Childs MT, Stimson C, et al. Effect of consumption of whole milk and skim milk on blood lipid profiles in healthy men. Am J Clin Nutr. Mar 1994;59(3):612-8. doi:10.1093/ajcn/59.3.612 | Sample size/Power
2226 | Stelmach-Mardas M, Walkowiak J, Zagrodzki P, Grygiel-Gorniak B, Przyslawski J. Lipid profile and non-cholesterol sterols in obese women’s serum after supplementing with plant stanol ester. Forsch Komplementmed. 2014;21(3):178-83. doi:10.1159/000357464 | Intervention/Exposure; Comparator
2227 | Steur M, Johnson L, Sharp SJ, et al. Dietary Fatty Acids, Macronutrient Substitutions, Food Sources and Incidence of Coronary Heart Disease: Findings From the EPIC-CVD Case-Cohort Study Across Nine European Countries. J Am Heart Assoc. Dec 7 2021;10(23):e019814. doi:10.1161/JAHA.120.019814 | Comparator
2228 | Stewart JW, Kaplan ML, Beitz DC. Pork with a high content of polyunsaturated fatty acids lowers LDL cholesterol in women. Am J Clin Nutr. Aug 2001;74(2):179-87. doi:10.1093/ajcn/74.2.179 | Sample size/Power
2229 | Stewart RA, Wallentin L, Benatar J, et al. Dietary patterns and the risk of major adverse cardiovascular events in a global study of high-risk patients with stable coronary heart disease. Eur Heart J. Jul 1 2016;37(25):1993-2001. doi:10.1093/eurheartj/ehw125 | Intervention/Exposure; Health status
2230 | Stocks T, Taylor MA, Angquist L, et al. Change in proportional protein intake in a 10-week energy-restricted low- or high-fat diet, in relation to changes in body size and metabolic factors. Journal article. Obes Facts. 2013;6(3):217-27. doi:10.1159/000351726 | Intervention/Exposure
2231 | Stoernell CK, Tangney CC, Rockway SW. Short-term changes in lipoprotein subclasses and C-reactive protein levels of hypertriglyceridemic adults on low-carbohydrate and low-fat diets. Nutr Res. Jul 2008;28(7):443-9. doi:10.1016/j.nutres.2008.03.013 | Intervention/Exposure
2232 | Stonehouse W, Sergi D, Benassi-Evans B, et al. Eucaloric diets enriched in palm olein, cocoa butter, and soybean oil did not differentially affect liver fat concentration in healthy participants: a 16-week randomized controlled trial. Am J Clin Nutr. Feb 2 2021;113(2):324-337. doi:10.1093/ajcn/nqaa347 | Sample size/Power
2233 | St-Onge MP, Aban I, Bosarge A, Gower B, Hecker KD, Allison DB. Snack chips fried in corn oil alleviate cardiovascular disease risk factors when substituted for low-fat or high-fat snacks. Am J Clin Nutr. 2007;85(6):1503-1510. doi:10.1093/ajcn/85.6.1503 | Intervention/Exposure; Duration
2234 | St-Onge MP, Bosarge A, Goree LL, Darnell B. Medium chain triglyceride oil consumption as part of a weight loss diet does not lead to an adverse metabolic profile when compared to olive oil. J Am Coll Nutr. Oct 2008;27(5):547-52. doi:10.1080/07315724.2008.10719737 | Intervention/Exposure; Sample size/Power
2235 | St-Onge MP, Farnworth ER, Savard T, Chabot D, Mafu A, Jones PJ. Kefir consumption does not alter plasma lipid levels or cholesterol fractional synthesis rates relative to milk in hyperlipidemic men: a randomized controlled trial [ISRCTN10820810]. BMC Complement Altern Med. 2002;2:1. doi:10.1186/1472-6882-2-1 | Intervention/Exposure; Sample size/Power
2236 | St-Onge MP, Goree LL, Gower B. High-milk supplementation with healthy diet counseling does not affect weight loss but ameliorates insulin action compared with low-milk supplementation in overweight children. J Nutr. May 2009;139(5):933-8. doi:10.3945/jn.108.102079 | Sample size/Power
2237 | St-Onge, MP, Zhang, S, Darnell, B, et al. Baseline serum C-reactive protein is associated with lipid responses to low-fat and high-polyunsaturated fat diets. J Nutr. 2009. 139:680-3. doi:10.3945/jn.108.098251 | Intervention/Exposure; Duration
2238 | Strand, MA, Perry, J, Wang, P, et al. Risk factors for metabolic syndrome in a cohort study in a north China urban middle-aged population. Asia Pac J Public Health. Mar 2015;27(2):NP255-65. doi:10.1177/1010539512438609 | Country
2239 | Straznicky, NE, Louis, WJ, McGrade, P, et al. The effects of dietary lipid modification on blood pressure, cardiovascular reactivity and sympathetic activity in man. J Hypertens. Apr 1993;11(4):427-37. doi:10.1097/00004872-199304000-00014 | Duration; Sample size/Power
2240 | Strengers, JG, den Ruijter, HM, Boer, JMA, et al. The association of the Mediterranean diet with heart failure risk in a Dutch population. Nutr Metab Cardiovasc Dis. 2021. 31:60-66. doi:10.1016/j.numecd.2020.08.003 | Intervention/Exposure
2241 | Streppel, MT, Sluik, D, van Yperen, JF, et al. Nutrient-rich foods, cardiovascular diseases and all-cause mortality: the Rotterdam study. Eur J Clin Nutr. 2014. 68:741-7. doi:10.1038/ejcn.2014.35 | Intervention/Exposure
2242 | Stuber, JM, Vissers, LET, Verschuren, WMM, et al. Substitution among milk and yogurt products and the risk of incident type 2 diabetes in the EPIC-NL cohort. J Hum Nutr Diet. 2021. 34:54-63. doi:10.1111/jhn.12767 | Outcome
2243 | Stupin, A, Rasic, L, Matic, A, et al. Omega-3 polyunsaturated fatty acids-enriched hen eggs consumption enhances microvascular reactivity in young healthy individuals. Appl Physiol Nutr Metab. 2018. 43:988-995. doi:10.1139/apnm-2017-0735 | Intervention/Exposure; Duration
2244 | Sugiyama, T, Xie, D, Graham-Maar, RC, et al. Dietary and lifestyle factors associated with blood pressure among U.S. adolescents. J Adolesc Health. 2007;40(2):166-172. doi:10.1016/j.jadohealth.2006.09.006 | Study design
2245 | Sun C, Zhang WS, Jiang CQ, et al. Low-Carbohydrate Diets and Mortality in Older Asian People: A 15-Year Follow-Up from a Prospective Cohort Study. Nutrients. 2022;14(7):1406. Published 2022 Mar 28. doi:10.3390/nu14071406 | Intervention/Exposure; Country
2246 | Sun, J, Buys, N, Shen, S. Dietary patterns and cardiovascular disease-related risks in chinese older adults. Front Public Health. 2013. 1:48. doi:10.3389/fpubh.2013.00048 | Study design; Intervention/Exposure; Country
2247 | Sun, J, Xu, D, Xie, H, et al. Low fat milk powder containing esterified plant sterols improves the blood lipid profile of adults with hypercholesterolemia. Zhonghua Xin Xue Guan Bing Za Zhi. Jul 2014;42(7):588-92. | Publication language
2248 | Sun, Q, Ma, J, Campos, H, et al. Plasma and erythrocyte biomarkers of dairy fat intake and risk of ischemic heart disease. Am J Clin Nutr. 2007. 86:929-37. doi:10.1093/ajcn/86.4.929 | Intervention/Exposure
2249 | Sun, X, Sun, R, Zhang, L. Red Meat Consumption and Risk of Cardio-Cerebrovascular Disease in Chinese Older Adults. Int Heart J. 2023. 64:654-662. doi:10.1536/ihj.23-138 | Country
2250 | Sun, Y, Chen, S, Zhao, X, et al. Adherence to the dietary approaches to stop hypertension diet and non-alcoholic fatty liver disease. Liver Int. Apr 2022;42(4):809-819. doi:10.1111/liv.15156 | Intervention/Exposure; Outcome
2251 | Sun, Y, Liu, B, Snetselaar, LG, et al. Association of fried food consumption with all cause, cardiovascular, and cancer mortality: prospective cohort study. Bmj. 2019. 364:k5420. doi:10.1136/bmj.k5420 | Intervention/Exposure
2252 | Sun, Y, Liu, B, Snetselaar, LG, et al. Chocolate Consumption in Relation to All-Cause and Cause-Specific Mortality in Women: The Women’s Health Initiative. J Acad Nutr Diet. 2023. 123:902-911.e3. doi:10.1016/j.jand.2022.12.007 | Comparator
2253 | Sundram, K, French, MA, Clandinin, MT. Exchanging partially hydrogenated fat for palmitic acid in the diet increases LDL-cholesterol and endogenous cholesterol synthesis in normocholesterolemic women. Eur J Nutr. 2003. 42:188-94. doi:10.1007/s00394-003-0411-9 | Sample size/Power
2254 | Sundram, K, Hayes, KC, Siru, OH. Dietary palmitic acid results in lower serum cholesterol than does a lauric-myristic acid combination in normolipemic humans. American Journal of Clinical Nutrition. Apr 1994;59(4):841-846. doi:DOI 10.1093/ajcn/59.4.841 | Sample size/Power
2255 | Sundram, K, Hornstra, G, von Houwelingen, AC, et al. Replacement of dietary fat with palm oil: effect on human serum lipids, lipoproteins and apolipoproteins. Circulation. Feb 13 2001;103(6):836-41. doi:10.1161/01.cir.103.6.836 | Comparator
2256 | Sundström J, Lind L, Vessby B, Andrén B, Aro A, Lithell H. Dyslipidemia and an unfavorable fatty acid profile predict left ventricular hypertrophy 20 years later. Circulation. 2001;103(6):836-841. doi:10.1161/01.cir.103.6.836 | Intervention/Exposure
2257 | Svahn, JC, Feldl, F, Räihä, NC, et al. Different quantities and quality of fat in milk products given to young children: effects on long chain polyunsaturated fatty acids and trans fatty acids in plasma. Acta Paediatr. 2002;91(1):20-9. doi:10.1080/080352502753457897 | Sample size/Power; Population
2258 | Svahn, JC, Feldl, F, Räihä, NC, et al. Fatty acid content of plasma lipid fractions, blood lipids, and apolipoproteins in children fed milk products containing different quantity and quality of fat. J Pediatr Gastroenterol Nutr. Aug 2000;31(2):152-61. doi:10.1097/00005176-200008000-00012 | Intervention/Exposure; Sample size/Power
2259 | Svetkey, LP, Moore, TJ, Simons-Morton, DG, et al. Angiotensinogen genotype and blood pressure response in the Dietary Approaches to Stop Hypertension (DASH) study. J Hypertens. Nov 2001;19(11):1949-56. doi:10.1097/00004872-20011100000004 | Intervention/Exposure
2260 | Svetkey, LP, Simons-Morton, D, Vollmer, WM, et al. Effects of dietary patterns on blood pressure: subgroup analysis of the Dietary Approaches to Stop Hypertension (DASH) randomized clinical trial. Arch Intern Med. 1999. 159:285-93. doi:10.1001/archinte.159.3.285 | Intervention/Exposure
2261 | Swain, JF, McCarron, PB, Hamilton, EF, et al. Characteristics of the diet patterns tested in the optimal macronutrient intake trial to prevent heart disease (OmniHeart): options for a heart-healthy diet. J Am Diet Assoc. 2008. 108:257-65. doi:10.1016/j.jada.2007.10.040 | Intervention/Exposure; Outcome
2262 | Sygnowska, E, Pardo, B, Waskiewicz, A. Sodium intake and prevalence of hypertension in the population covered by the Warsaw-Pol-Monica Project. Cardiovascular Risk Factors. 1992. 2:239. | Intervention/Exposure
2263 | Szostak, WB, Sekuła, W, Figurska, K. Reduction of cardiovascular mortality in Poland and changes in dietary patterns. Kardiol Pol. Mar 2003;58(3):173-81; discussion 180-1. | Study design
2264 | Szymlek-Gay, EA, Gray, AR, Heath, ALM, et al. Red meat consumption and serum lipids and fatty acids in toddlers: Secondary outcomes of a randomized controlled trial. J Pediatr Gastroenterol Nutr. Sep 2018;67(3):395-400. doi:10.1097/MPG.0000000000002018 | Population
2265 | Szypowska A, Regulska-Ilow B, Zatońska K, Szuba A. Comparison of Intake of Food Groups Based on Dietary Inflammatory Index (DII) and Cardiovascular Risk Factors in the Middle-Age Population of Lower Silesia: Results of the PURE Poland Study. Antioxidants (Basel). 2023;12(2):285. Published 2023 Jan 27. doi:10.3390/antiox12020285 | Intervention/Exposure
2266 | Szypowska, A, Zatońska, K, Szuba, A, et al. Dietary Inflammatory Index (DII)® and Metabolic Syndrome in the Selected Population of Polish Adults: Results of the PURE Poland Sub-Study. Int J Environ Res Public Health. 2023;20(2):1056. Published 2023 Jan 6. doi:10.3390/ijerph20021056 | Intervention/Exposure; Outcome
2267 | Takano, T. Anti-hypertensive activity of fermented dairy products containing biogenic peptides. Antonie Van Leeuwenhoek. Aug 2002;82(1-4):333-40. | Study design; Non-human
2268 | Takata, Y, Shu, XO, Gao, YT, et al. Red meat and poultry intakes and risk of total and cause-specific mortality: results from cohort studies of Chinese adults in Shanghai. PLoS One. 2013. 8:e56963. doi:10.1371/journal.pone.0056963 | Country
2269 | Talaei, M, Hosseini, N, van Dam, RM, et al. Whole milk consumption and risk of cardiovascular disease and mortality: Isfahan Cohort Study. Eur J Nutr. Feb 2019;58(1):163-171. doi:10.1007/s00394-017-1581-1 | Comparator
2270 | Talaei, M, Koh, WP, Yuan, JM, et al. The association between dairy product intake and cardiovascular disease mortality in Chinese adults. J Nutr. Feb 2017;147(2):235-241. doi:10.3945/jn.116.238485 | Intervention/Exposure; Comparator
2271 | Talaei, M, Pan, A, Yuan, JM, et al. Dairy Food Intake Is Inversely Associated with Risk of Hypertension: The Singapore Chinese Health Study. J Nutr. 2017. 147:235-241. doi:10.3945/jn.116.238485 | Intervention/Exposure; Comparator
2272 | Tamai, T, Murota, I, Baba, T, et al. Effects of fish hamburger enriched with docosahexaenoic acid and eicosapentaenoic acid on serum lipids in clinical trials of intake for three months, and safety evaluation of excessive intake. Japanese Pharmacology and Therapeutics. 2008. 36:333-345. | Publication language
2273 | Tammi, A, Rönnemaa, T, Gylling, H, et al. Plant stanol ester margarine lowers serum total and low-density lipoprotein cholesterol concentrations of healthy children: the STRIP project. Special Turku Coronary Risk Factors Intervention Project. J Pediatr. Apr 2000;136(4):503-10. doi:10.1016/s0022-3476(00)90014-3 | Intervention/Exposure; Comparator
2274 | Tammi, A, Rönnemaa, T, Miettinen, TA, et al. Effects of gender, apolipoprotein E phenotype and cholesterol-lowering by plant stanol esters in children: the STRIP study. Special Turku Coronary Risk Factor Intervention Project. Acta Paediatr. 2002;91(11):1155-62. doi:10.1080/080352502320777379 | Intervention/Exposure
2275 | Tamura, T, Wakai, K, Kato, Y, et al. Dietary Carbohydrate and Fat Intakes and Risk of Mortality in the Japanese Population: the Japan Multi-Institutional Collaborative Cohort Study. J Nutr. 2023;153(8):2352-2368. doi:10.1016/j.tjnut.2023.05.027 | Intervention/Exposure
2276 | Tan, DT, Khor, HT, Low, WH, et al. Effect of a palm-oil-vitamin E concentrate on the serum and lipoprotein lipids in humans. Am J Clin Nutr. Apr 1991;53(4 Suppl):1027S-1030S. doi:10.1093/ajcn/53.4.1027S | Study design; Sample size/Power
2277 | Tan LJ, Jeon HJ, Park S, et al. Association of Coffee Consumption and Its Types According to Addition of Sugar and Creamer with Metabolic Syndrome Incidence in a Korean Population from the Health Examinees (HEXA) Study. Nutrients. 2021;13(3):920. Published 2021 Mar 12. doi:10.3390/nu13030920 | Intervention/Exposure
2278 | Tanaka, S, Uenishi, K, Ishida, H, et al. A randomized intervention trial of 24-wk dairy consumption on waist circumference, blood pressure, and fasting blood sugar and lipids in Japanese men with metabolic syndrome. J Nutr Sci Vitaminol (Tokyo). 2014. 60:305-12. doi:10.3177/jnsv.60.305 | Intervention/Exposure; Comparator
2279 | Tang, M, Armstrong, CL, Leidy, HJ, et al. Normal vs. high-protein weight loss diets in men: effects on body composition and indices of metabolic syndrome. Obesity (Silver Spring). Mar 2013;21(3):E204-10. doi:10.1002/oby.20078 | Intervention/Exposure; Sample size/Power
2280 | Tang, Z, Zhou, T, Luo, Y, et al. Risk factors for cerebrovascular disease mortality among the elderly in Beijing: a competing risk analysis. PLoS One. 2014. 9:e87884. doi:10.1371/journal.pone.0087884 | Country
2281 | Tanno, K, Yonekura, Y, Okuda, N, et al. Association between Milk Intake and Incident Stroke among Japanese Community Dwellers: The Iwate-KENCO Study. Nutrients. 2021. 13. doi:10.3390/nu13113781 | Comparator
2282 | Taubert, D, Berkels, R, Roesen, R, et al. Chocolate and blood pressure in elderly individuals with isolated systolic hypertension. JAMA. Aug 27 2003;290(8):1029-30. doi:10.1001/jama.290.8.1029 | Publication status; Sample size/Power
2283 | Taubert, D, Roesen, R, Lehmann, C, et al. Effects of low habitual cocoa intake on blood pressure and bioactive nitric oxide: a randomized controlled trial. JAMA. 2007. 298:49-60. doi:10.1001/jama.298.1.49 | Intervention/Exposure; Comparator
2284 | Tavani, A, Gallus, S, Negri, E, et al. Milk, dairy products, and coronary heart disease. J Epidemiol Community Health. 2002. 56:471-2. doi:10.1136/jech.56.6.471 | Study design
2285 | Tavani, A, Negri, E, D’Avanzo, B, et al. Margarine intake and risk of nonfatal acute myocardial infarction in Italian women. Eur J Clin Nutr. Jan 1997;51(1):30-2. doi:10.1038/sj.ejcn.1600356 | Study design; Intervention/Exposure
2286 | Tavares, AKMM, Ribas, SA, Paravidino, VB, et al. Effect of phytosterol capsule supplementation associated with the National Cholesterol Education Program Step 2 diet on low-density lipoprotein in children and adolescents with dyslipidemia: A double-blind crossover trial. Nutrition. Feb 2021;82:111051. doi:10.1016/j.nut.2020.111051 | Intervention/Exposure
2287 | Tay, W, Quek, R, Lim, J, et al. Plant-based alternative proteins-are they nutritionally more advantageous?. Eur J Clin Nutr. 2023. 77:1051-1060. doi:10.1038/s41430-02301328-1 | Study design; Outcome
2288 | Taylor, DM, Pye, CL, Hindson, RM, et al. Lipid levels of expeditioners in Antarctica: response to a reduced-fat, oleic acid and carbohydrate-enriched diet. Arctic Med Res. Oct 1995;54(4):160-9. | Intervention/Exposure
2289 | Tayyem, RF, Al-Shudifat, AE, Hammad, S, et al. Fat intake and the risk of coronary heart disease among Jordanians. Nutricion Hospitalaria. Mar-Apr 2020;37(2):313-320. doi:10.20960/nh.02761 | Study design
2290 | Te Morenga, LA, Levers, MT, Williams, SM, et al. Comparison of high protein and high fiber weight-loss diets in women with risk factors for the metabolic syndrome: A randomized trial. Nutr J. Apr 28 2011;10:40. doi:10.1186/1475-2891-10-40 | Intervention/Exposure
2291 | te Velde, SJ, Snijder, MB, van Dijk, AE, et al. Dairy intake from adolescence into adulthood is not associated with being overweight and metabolic syndrome in adulthood: the Amsterdam Growth and Health Longitudinal Study. J Hum Nutr Diet. 2011;24(3):233-244. doi:10.1111/j.1365-277X.2010.01149.x | Comparator
2292 | Teisen, MN, Vuholm, S, Rantanen, JM, et al. Exploring the effects of oily fish consumption on measures of acute and long-term stress in healthy 8-9-year-old children: The FiSK Junior randomised trial. British Journal of Nutrition. 2021. 126:1194-1202. doi:10.1017/S000711452000519X | Intervention/Exposure; Comparator
2293 | Teixeira Rde, C, Molina Mdel, C, Zandonade, E, et al. Cardiovascular risk in vegetarians and omnivores: a comparative study. Arq Bras Cardiol. Oct 2007;89(4):237-44. doi:10.1590/s0066-782x2007001600005 | Intervention/Exposure; Country
2294 | Tektonidis, TG, . A Mediterranean diet and risk of myocardial infarction, heart failure and stroke: A population-based cohort study. Atherosclerosis. Nov 2015;243(1):93-8. doi:10.1016/j.atherosclerosis.2015.08.039 | Intervention/Exposure
2295 | Tell, GS, Evans, GW, Folsom, AR, et al. Dietary fat intake and carotid artery wall thickness: the Atherosclerosis Risk in Communities (ARIC) Study. Am J Epidemiol. May 15 1994;139(10):979-89. doi:10.1093/oxfordjournals.aje.a116947 | Intervention/Exposure; Outcome
2296 | Telle-Hansen, VH, Narverud, I, Retterstol, K, et al. Substitution of TAG oil with diacylglycerol oil in food items improves the predicted 10 years cardiovascular risk score in healthy, overweight subjects. J Nutr Sci. 2012;1:e17. doi:10.1017/jns.2012.18 | Intervention/Exposure; Sample size/Power
2297 | Temme, EH, Mensink, RP, Hornstra, G. Comparison of the effects of diets enriched in lauric, palmitic, or oleic acids on serum lipids and lipoproteins in healthy women and men. Am J Clin Nutr. 1996. 63:897-903. doi:10.1093/ajcn/63.6.897 | Intervention/Exposure; Comparator
2298 | Temme, EH, Mensink, RP, Hornstra, G. Effects of medium chain fatty acids (MCFA), myristic acid, and oleic acid on serum lipoproteins in healthy subjects. J Lipid Res. 1997. 38:1746-54. | Intervention/Exposure; Duration
2299 | Temme, EH, Mensink, RP, Hornstra, G. Individual saturated fatty acids and effects on whole blood aggregation in vitro. Eur J Clin Nutr. Oct 1998;52(10):697-702. doi:10.1038/sj.ejcn.1600626 | Intervention/Exposure
2300 | Temporelli, PL. Cardiovascular prevention: Mediterranean or low-fat diet?. Eur Heart J Suppl. 2023. 25:B166-b170. doi:10.1093/eurheartjsupp/suad097 | Study design
2301 | Tenconi, MT, Romanelli, C, Gigli, F, et al. The relationship between education and risk factors for coronary heart disease. Epidemiological analysis from the nine communities study. The Research Group ATS-OB43 of CNR. Eur J Epidemiol. 1992;8(6):763-769. doi:10.1007/BF00145317 | Intervention/Exposure
2302 | Teng, KT, Chang, LF, Vethakkan, SR, et al. Effects of exchanging carbohydrate or monounsaturated fat with saturated fat on inflammatory and thrombogenic responses in subjects with abdominal obesity: A randomized controlled trial. Clin Nutr. Oct 2017;36(5):1250-1258. doi:10.1016/j.clnu.2016.08.026 | Intervention/Exposure
2303 | Teunissen-Beekman, KF, Dopheide, J, Geleijnse, JM, et al. Protein supplementation lowers blood pressure in overweight adults: effect of dietary proteins on blood pressure (PROPRES), a randomized trial. Am J Clin Nutr. Apr 2012;95(4):966-71. doi:10.3945/ajcn.111.029116 | Intervention/Exposure
2304 | Teymoori, F, Asghari, G, Farhadnejad, H, et al. Various proline food sources and blood pressure: substitution analysis. Int J Food Sci Nutr. 2020. 71:332-340. doi:10.1080/09637486.2019.1650004 | Intervention/Exposure
2305 | Thams, L, Stounbjerg, NG, Hvid, LG, et al. Effects of high dairy protein intake and vitamin D supplementation on body composition and cardiometabolic markers in 6-8-y-old children-the D-pro trial. Am J Clin Nutr. 2022. 115:1080-1091. doi:10.1093/ajcn/nqab424 | Intervention/Exposure; Comparator
2306 | Tharrey, M, Mariotti, F, Mashchak, A, et al. Patterns of plant and animal protein intake are strongly associated with cardiovascular mortality: the Adventist Health Study-2 cohort. Int J Epidemiol. 2018. 47:1603-1612. doi:10.1093/ije/dyy030 | Intervention/Exposure
2307 | The devil in the dark chocolate. Lancet. 2007. 370(9605):2070. doi:10.1016/S0140-6736(07)61873-X | Study design
2308 | The role of dairy products in diet. Introduction. J Am Coll Nutr. 2009;28 Suppl 1:69S-72S. | Study design; Publication status
2309 | Thiengwiboonwong, S. Efficacy of dietary modification following the National Cholesterol Education Program (NCEP) recommendation on lipid profiles among hyperlipidemia subjects. J Med Assoc Thai. 2013;96(10):1257-1267. | Intervention/Exposure
2310 | Thijssen, MA, Hornstra, G, Mensink, RP. Stearic, oleic, and linoleic acids have comparable effects on markers of thrombotic tendency in healthy human subjects. J Nutr. 2005. 135:2805-11. doi:10.1093/jn/135.12.2805 | Intervention/Exposure
2311 | Thijssen, MA, Mensink, RP. Small differences in the effects of stearic acid, oleic acid, and linoleic acid on the serum lipoprotein profile of humans. Am J Clin Nutr. 2005. 82:510-6. doi:10.1093/ajcn.82.3.510 | Intervention/Exposure
2312 | Tholstrup, T, Hjerpsted, J, Raff, M. Palm olein increases plasma cholesterol moderately compared with olive oil in healthy individuals. Am J Clin Nutr. 2011. 94:1426-32. doi:10.3945/ajcn.111.018846 | Duration
2313 | Tholstrup, T, Høy, CE, Andersen, LN, et al. Does fat in milk, butter and cheese affect blood lipids and cholesterol differently?. J Am Coll Nutr. 2004;23(2):169-176. doi:10.1080/07315724.2004.10719358 | Sample size/Power
2314 | Tholstrup, T, Marckmann, P, Hermansen, J, et al. Effect of modified dairy fat on fasting and postprandial haemostatic variables in healthy young men. Br J Nutr. 1999. 82:105-13. | Duration; Sample size/Power
2315 | Tholstrup, T, Raff, M, Basu, S, et al. Effects of butter high in ruminant trans and monounsaturated fatty acids on lipoproteins, incorporation of fatty acids into lipid classes, plasma C-reactive protein, oxidative stress, hemostatic variables, and insulin in healthy young men. Am J Clin Nutr. 2006. 83:237-43. doi:10.1093/ajcn/83.2.237 | Comparator; Sample size/Power
2316 | Tholstrup, T, Sandström, B, Hermansen, JE, et al. Effect of modified dairy fat on postprandial and fasting plasma lipids and lipoproteins in healthy young men. Lipids. 1998. 33:11-21. doi:10.1007/s11745-998-0175-0 | Sample size/Power
2317 | Thomas, IM. Changes in Food Sources of Calcium, Potassium, and Magnesium in the Diets of Adolescents with Hypertension in Response to a Behavioral Nutrition Intervention Emphasizing Fruit, Vegetable, and Lowfat Dairy Foods. Thesis. Brigham Young University, thesis. 2011. | Study design; Publication status
2318 | Thompson, WG, Rostad Holdman, N, Janzow, DJ, et al. Effect of energy-reduced diets high in dairy products and fiber on weight loss in obese adults. Obes Res. Aug 2005;13(8):1344-53. doi:10.1038/oby.2005.163 | Sample size/Power
2319 | Thorning, TK, Raziani, F, Bendsen, NT, et al. Diets with high-fat cheese, high-fat meat, or carbohydrate on cardiovascular risk markers in overweight postmenopausal women: a randomized crossover trial. Am J Clin Nutr. 2015. 102:573-81. doi:10.3945/ajcn.115.109116 | Duration
2320 | Thorogood, M, Mann, J, Appleby, P, et al. Risk of death from cancer and ischaemic heart disease in meat and non-meat eaters. British Medical Journal. 1994. 308:1667-1670. doi:10.1136/bmj.308.6945.1667 | Comparator
2321 | Thorp, AA, Howe, PR, Mori, TA, et al. Soy food consumption does not lower LDL cholesterol in either equol or nonequol producers. American Journal of Clinical Nutrition. Aug 1 2008;88(2):298-304. doi:DOI 10.1093/ajcn/88.2.298 | Intervention/Exposure
2322 | Tian, HG, Nan, Y, Liang, XQ, et al. Relationship between serum lipids and dietary and non-dietary factors in a Chinese population. European Journal of Clinical Nutrition. Dec 1995;49(12):871-882. | Study design; Intervention/Exposure
2323 | Tierney, AC, McMonagle, J, Shaw, DI, et al. Effects of dietary fat modification on insulin sensitivity and on other risk factors of the metabolic syndrome-LIPGENE: a European randomized dietary intervention study. Int J Obes (Lond). Jun 2011;35(6):800-9. doi:10.1038/ijo.2010.209 | Intervention/Exposure
2324 | Tikkanen, MJ, Högström, P, Tuomilehto, J, et al. Effect of a diet based on low-fat foods enriched with nonesterified plant sterols and mineral nutrients on serum cholesterol. Am J Cardiol. Nov 15 2001;88(10):1157-62. doi:10.1016/s0002-9149(01)02053-7 | Intervention/Exposure
2325 | Tikkanen, MJ, Huttunen, JK, Ehnholm, C, et al. Apolipoprotein E4 homozygosity predisposes to serum cholesterol elevation during high fat diet. Arteriosclerosis. Mar-Apr 1990;10(2):285-8. doi:10.1161/01.atv.10.2.285 | Intervention/Exposure
2326 | Tillotson JL, Bartsch GE, Gorder D, Grandits GA, Stamler J. Food group and nutrient intakes at baseline in the Multiple Risk Factor Intervention Trial. Am J Clin Nutr. 1997;65(1 Suppl):228S-257S. doi:10.1093/ajcn/65.1.228S | Study design
2327 | Timmermans, S, Steegers-Theunissen, RP, Vujkovic, M, et al. Major dietary patterns and blood pressure patterns during pregnancy: the Generation R Study. Am J Obstet Gynecol. 2011. 205:337.e1-12. doi:10.1016/j.ajog.2011.05.013 | Intervention/Exposure
2328 | Tindall, AM, Kris-Etherton, PM, Petersen, KS. Replacing Saturated Fats with Unsaturated Fats from Walnuts or Vegetable Oils Lowers Atherogenic Lipoprotein Classes Without Increasing Lipoprotein(a). J Nutr. 2020. 150:818-825. doi:10.1093/jn/nxz313 | Intervention/Exposure
2329 | Tisdel, DM, Gadberry, JJ, Burke, SL, et al. Dietary fat and alcohol in the prediction of indices of vascular health among young adults. Nutrition. Apr 2021;84doi:ARTN 11112010.1016/j.nut.2020.111120 | Study design; Outcome
2330 | TJW McDonald, L Diaz-Arias, D Vizthum, BJ Henry-Barron, MC Cervenka. Predictors of elevations in fasting lipid levels in adults with epilepsy on a modified Atkins diet. Seizure. Dec 2023;113:86-92. doi:10.1016/j.seizure.2023.11.012 | Intervention/Exposure; Health status
2331 | Toft, U, Kristoffersen, L, Ladelund, S, et al. The impact of a population-based multi-factorial lifestyle intervention on changes in long-term dietary habits: the Inter99 study. Prev Med. 2008. 47:378-83. doi:10.1016/j.ypmed.2008.05.013 | Intervention/Exposure; Outcome
2332 | Tognon, G, Rothenberg, E, Eiben, G, et al. Does the Mediterranean diet predict longevity in the elderly? A Swedish perspective. Age. 2011. 33:439-450. doi:10.1007/s11357-010-9193-1 | Intervention/Exposure; Outcome
2333 | Toledo, E, Delgado-Rodríguez, M, Estruch, R, et al. Low-fat dairy products and blood pressure: follow-up of 2290 older persons at high cardiovascular risk participating in the PREDIMED study. Br J Nutr. 2009. 101:59-67. doi:10.1017/s0007114508981496 | Comparator
2334 | Tong, TYN, Appleby, PN, Bradbury, KE, et al. Risks of ischaemic heart disease and stroke in meat eaters, fish eaters, and vegetarians over 18 years of follow-up: results from the prospective EPIC-Oxford study. Bmj. 2019. 366:l4897. doi:10.1136/bmj.l4897 | Comparator
2335 | Tong, TYN, Appleby, PN, Key, TJ, et al. The associations of major foods and fibre with risks of ischaemic and haemorrhagic stroke: a prospective study of 418 329 participants in the EPIC cohort across nine European countries. Eur Heart J. 2020. 41:2632-2640. doi:10.1093/eurheartj/ehaa007 | Comparator
2336 | Tong, TYN, Perez-Cornago, A, Bradbury, KE, et al. Biomarker Concentrations in White and British Indian Vegetarians and Nonvegetarians in the UK Biobank. J Nutr. 2021. 151:3168-3179. doi:10.1093/jn/nxab192 | Study design; Outcome
2337 | Tonstad, S, Strøm, EC, Bergei, CS, et al. Serum cholesterol response to replacing butter with a new trans-free margarine in hypercholesterolemic subjects. Nutr Metab Cardiovasc Dis. Oct 2001;11(5):320-6. | Duration
2338 | Tonstad, S, Sundfør, T, Seljeflot, I. Effect of lifestyle changes on atherogenic lipids and endothelial cell adhesion molecules in young adults with familial premature coronary heart disease. Am J Cardiol. May 15 2005;95(10):1187-91. doi:10.1016/j.amjcard.2005.01.047 | Intervention/Exposure; Health status
2339 | Torres, SJ, Nowson, CA. Effect of a weight-loss program on mental stress-induced cardiovascular responses and recovery. Nutrition. Jul-Aug 2007;23(7-8):521-8. doi:10.1016/j.nut.2007.04.016 | Intervention/Exposure
2340 | Torvik, K, Narverud, I, Ottestad, I, et al. Dietary counseling is associated with an improved lipid profile in children with familial hypercholesterolemia. Atherosclerosis. Sep 2016;252:21-27. | Intervention/Exposure
2341 | Towle, LA, Bergman, EA, Joseph, E. Low-fat bison-hybrid ground meat has no effects on serum lipid levels in a study of 12 men. Journal of the American Dietetic Association. May 1994;94(5):546-548. doi:Doi 10.1016/0002-8223(94)90221-6 | Sample size/Power
2342 | Trébuchet, A, Julia, C, Fézeu, L, et al. Prospective association between several dietary scores and risk of cardiovascular diseases: Is the Mediterranean diet equally associated to cardiovascular diseases compared to National Nutritional Scores?. Am Heart J. 2019;217:1-12. doi:10.1016/j.ahj.2019.07.009 | Intervention/Exposure
2343 | Trepanowski, JF, Kabir, MM, Alleman, RJ, et al. A 21-day Daniel fast with or without krill oil supplementation improves anthropometric parameters and the cardiometabolic profile in men and women. Nutr Metab (Lond). 2012. 9:82. doi:10.1186/1743-7075-9-82 | Duration
2344 | Trevisan, M, Krogh, V, Freudenheim, JL, et al. Diet and coronary heart disease risk factors in a population with varied intake. The Research Group ATS-RF2 of The Italian National Research Council. Prev Med. May 1990;19(3):231-41. doi:10.1016/0091-7435(90)90024-e | Study design; Intervention/Exposure
2345 | Triche, EW, Grosso, LM, Belanger, K, et al. Chocolate consumption in pregnancy and reduced likelihood of preeclampsia. Epidemiology. May 2008;19(3):459-64. doi:10.1097/EDE.0b013e31816a1d17 | Outcome
2346 | Trichia, E, Luben, R, Khaw, KT, et al. The associations of longitudinal changes in consumption of total and types of dairy products and markers of metabolic risk and adiposity: findings from the European Investigation into Cancer and Nutrition (EPIC)-Norfolk study, United Kingdom. Am J Clin Nutr. 2020. 111:1018-1026. doi:10.1093/ajcn/nqz335 | Comparator
2347 | Trichopoulou, A, Bamia, C, Trichopoulos, D. Anatomy of health effects of Mediterranean diet: Greek EPIC prospective cohort study. Bmj. 2009. 338:b2337. doi:10.1136/bmj.b2337 | Outcome
2348 | Tricon, S, Burdge, GC, Jones, EL, et al. Effects of dairy products naturally enriched with cis-9,trans-11 conjugated linoleic acid on the blood lipid profile in healthy middle-aged men. American journal of clinical nutrition. 2006. 83:744-753. doi:10.1093/ajcn/83.4.744 | Intervention/Exposure
2349 | Trouwborst, I, Goossens, GH, Astrup, A, et al. Sexual dimorphism in body weight loss, improvements in cardiometabolic risk factors and maintenance of beneficial effects 6 months after a low-calorie diet: Results from the randomized controlled diogenes trial. Nutrients. May 10 2021;13(5)doi:10.3390/nu13051588 | Intervention/Exposure
2350 | Trude, AC, Kharmats, A, Jock, B, et al. Patterns of Food Consumption are Associated with Obesity, Self-Reported Diabetes and Cardiovascular Disease in Five American Indian Communities. Ecol Food Nutr. 2015;54(5):437-54. doi:10.1080/03670244.2014.922070 | Study design
2351 | Tsaban, G, Yaskolka Meir, A, Rinott, E, et al. The effect of green Mediterranean diet on cardiometabolic risk; A randomised controlled trial. Heart. Jun 11 2021;107(13):1054-1061. doi:10.1136/heartjnl-2020-317802 | Intervention/Exposure
2352 | Tsai, YH, Park, S, Kovacic, J, et al. Mechanisms mediating lipoprotein responses to diets with medium-chain triglyceride and lauric acid. Lipids. 1999. 34:895-905. doi:10.1007/s11745-999-0438-9 | Intervention/Exposure; Sample size/Power
2353 | Tsoi, KY, Chan, RSM, Tam, CHT, et al. Dietary patterns of Chinese pregnant women in Hong Kong. Asia Pac J Clin Nutr. 2022. 31:378-393. doi:10.6133/apjcn.202209_31(3).0006 | Intervention/Exposure
2354 | Tsygankova, DP, Bazdyrev, ED, Agienko, AS, et al. Cardioprotective dietary pattern of Siberian population. Russian Open Medical Journal. Sep 2023;12(3) doi:ARTN e030210.15275/rusomj.2023.0302 | Publication status
2355 | Tuccinardi, D, Di Mauro, A, Lattanzi, G, et al. An extra virgin olive oil-enriched chocolate spread positively modulates insulin-resistance markers compared with a palm oil-enriched one in healthy young adults: a double-blind, cross-over, randomised controlled trial. Diabetes/metabolism research and reviews. 2022. 38:e3492. doi:10.1002/dmrr.3492 | Duration; Sample size/Power
2356 | Tucker, K. Dietary patterns and blood pressure in African Americans. Nutrition reviews. 1999. 57:356-358. doi:10.1111/j.1753-4887.1999.tb06914.x | Intervention/Exposure
2357 | Tucker, KL, Hallfrisch, J, Qiao, N, et al. The combination of high fruit and vegetable and low saturated fat intakes is more protective against mortality in aging men than is either alone: the Baltimore Longitudinal Study of Aging. J Nutr. 2005. 135:556-61. doi:10.1093/jn/135.3.556 | Intervention/Exposure
2358 | Tuleuova, R, Zhamaliyeva, L, Grjibovski, A. Dietary Factors and Changes in Blood Pressure in Adult Kazakhs: A 3-year Follow-Up Study. Open Access Macedonian Journal of Medical Sciences. 10(B):2146-2152. doi:10.3889/oamjms.2022.10287 | Study design; Intervention/Exposure
2359 | Turley, ML, Skeaff, CM, Mann, JI, et al. The effect of a low-fat, high-carbohydrate diet on serum high density lipoprotein cholesterol and triglyceride. Eur J Clin Nutr. Oct 1998;52(10):728-32. doi:10.1038/sj.ejcn.1600634 | Intervention/Exposure
2360 | Turner, KM, Keogh, JB, Clifton, PM. Acute effect of red meat and dairy on glucose and insulin: a randomized crossover study. Am J Clin Nutr. 2016. 103:71-6. doi:10.3945/ajcn.115.123505 | Duration
2361 | Turner, KM, Keogh, JB, Meikle, PJ, et al. Changes in Lipids and Inflammatory Markers after Consuming Diets High in Red Meat or Dairy for Four Weeks. Nutrients. 2017. 9:886. doi:10.3390/nu9080886 | Intervention/Exposure
2362 | Turpeinen, AM, Basu, S, Mutanen, M. A high linoleic acid diet increases oxidative stress in vivo and affects nitric oxide metabolism in humans. Prostaglandins Leukot Essent Fatty Acids. 1998;59(3):229-233. doi:10.1016/s0952-3278(98)90067-9 | Intervention/Exposure; Outcome
2363 | Turpeinen, AM, Ikonen, M, Kivimäki, AS, et al. A spread containing bioactive milk peptides Ile-Pro-Pro and Val-Pro-Pro, and plant sterols has antihypertensive and cholesterol-lowering effects. Food Funct. 2012. 3:621-7. doi:10.1039/c2fo10286b | Intervention/Exposure; Comparator
2364 | Tymchuk, CN, Tessler, SB, Barnard, RJ. Changes in sex hormone-binding globulin, insulin, and serum lipids in postmenopausal women on a low-fat, high-fiber diet combined with exercise. Nutr Cancer. 2000. 38:158-62. doi:10.1207/s15327914nc382_3 | Duration; Sample size/Power
2365 | Tzelefa, V, Tsirimiagkou, C, Argyris, A, et al. Associations of dietary patterns with blood pressure and markers of subclinical arterial damage in adults with risk factors for CVD. Public Health Nutr. 2021. 24:6075-6084. doi:10.1017/s1368980021003499 | Intervention/Exposure
2366 | Ueshima, H, Okayama, A, Saitoh, S, et al. Differences in cardiovascular disease risk factors between Japanese in Japan and Japanese-Americans in Hawaii: the INTERLIPID study. Journal of Human Hypertension. Sep 2003;17(9):631-639. doi:10.1038/sj.jhh.1001606 | Intervention/Exposure; Outcome
2367 | Ulven, SM, Leder, L, Elind, E, et al. Exchanging a few commercial, regularly consumed food items with improved fat quality reduces total cholesterol and LDL-cholesterol: a double-blind, randomised controlled trial. Br J Nutr. Oct 2016;116(8):1383-1393. doi:10.1017/S0007114516003445 | Intervention/Exposure
2368 | Um, CY, Judd, SE, Flanders, WD, et al. Associations of Calcium and Dairy Products with All-Cause and Cause-Specific Mortality in the REasons for Geographic and Racial Differences in Stroke (REGARDS) Prospective Cohort Study. Nutr Cancer. 2017. 69:1185-1195. doi:10.1080/01635581.2017.1367946 | Comparator
2369 | Um, CY, Prizment, A, Hong, CP, et al. Associations of calcium and dairy product intakes with all-cause, all-cancer, colorectal cancer and CHD mortality among older women in the Iowa Women’s Health Study. Br J Nutr. 2019. 121:1188-1200. doi:10.1017/s000711451900045x | Comparator
2370 | Um, YJ, Oh, SW, Lee, CM, et al. Dietary Fat Intake and the Risk of Metabolic Syndrome in Korean Adults. Korean J Fam Med. 2015. 36:245-52. doi:10.4082/kjfm.2015.36.5.245 | Intervention/Exposure; Outcome
2371 | Umemura, U, Ishimori, M, Kobayashi, T, et al. Possible effects of diets on serum lipids, fatty acids and blood pressure levels in male and female Japanese university students. Environ Health Prev Med. Jan 2005;10(1):42-7. doi:10.1265/ehpm.10.42 | Study design; Intervention/Exposure
2372 | Umesawa, M, Iso, H, Ishihara, J, et al. Dietary calcium intake and risks of stroke, its subtypes, and coronary heart disease in Japanese: the JPHC Study Cohort I. Stroke. Sep 2008;39(9):2449-56. doi:10.1161/STROKEAHA.107.512236 | Intervention/Exposure
2373 | Umesawa, M, Kitamura, A, Kiyama, M, et al. Association between dietary behavior and risk of hypertension among Japanese male workers. Hypertension Research. Apr 2013;36(4):374-380. doi:10.1038/hr.2012.205 | Intervention/Exposure; Comparator
2374 | Urquiaga, I, Guasch, V, Marshall, G, et al. Effect of Mediterranean and Occidental diets, and red wine, on plasma fatty acids in humans. An intervention study. Biol Res. 2004. 37:253-61. doi:10.4067/s0716-97602004000200012 | Intervention/Exposure
2375 | Urquiaga, I, Troncoso, D, Mackenna, MJ, et al. The Consumption of Beef Burgers Prepared with Wine Grape Pomace Flour Improves Fasting Glucose, Plasma Antioxidant Levels, and Oxidative Damage Markers in Humans: A Controlled Trial. Nutrients. 2018. 10. doi:10.3390/nu10101388 | Intervention/Exposure; Sample size/Power
2376 | Ushula, TW, Mamun, A, Darssan, D, et al. Dietary patterns and the risk of abnormal blood lipids among young adults: A prospective cohort study. Nutr Metab Cardiovasc Dis. 2022. 32:1165-1174. doi:10.1016/j.numecd.2022.01.030 | Intervention/Exposure
2377 | Ushula, TW, Mamun, A, Darssan, D, et al. Dietary patterns and the risks of metabolic syndrome and insulin resistance among young adults: Evidence from a longitudinal study. Clinical Nutrition. 2022. 41:1523-1531. doi:10.1016/j.clnu.2022.05.006 | Intervention/Exposure
2378 | Ushula, TW, Mamun, A, Darssan, D, et al. Dietary patterns explaining variations in blood biomarkers in young adults are associated with the 30-year predicted cardiovascular disease risks in midlife: A follow-up study. Nutr Metab Cardiovasc Dis. 2023. 33:1007-1018. doi:10.1016/j.numecd.2023.02.019 | Intervention/Exposure
2379 | Usinger, L, Jensen, LT, Flambard, B, et al. The antihypertensive effect of fermented milk in individuals with prehypertension or borderline hypertension. J Hum Hypertens. Oct 2010;24(10):678-83. doi:10.1038/jhh.2010.4 | Intervention/Exposure
2380 | Utzschneider, KM, Bayer-Carter, JL, Arbuckle, MD, et al. Beneficial effect of a weight-stable, low-fat/low-saturated fat/low-glycaemic index diet to reduce liver fat in older subjects. Br J Nutr. Mar 28 2013;109(6):1096-104. doi:10.1017/S0007114512002966 | Intervention/Exposure
2381 | Uusitupa, M, Hermansen, K, Savolainen, MJ, et al. Effects of an isocaloric healthy Nordic diet on insulin sensitivity, lipid profile and inflammation markers in metabolic syndrome - a randomized study (SYSDIET). Journal of internal medicine. 2013. 274:52-66. doi:10.1111/joim.12044 | Intervention/Exposure
2382 | Uusitupa, M, Louheranta, A, Lindström, J, et al. The Finnish Diabetes Prevention Study. Br J Nutr. 2000. 83 Suppl 1:S137-42. doi:10.1017/s0007114500001070 | Intervention/Exposure
2383 | Uusitupa, MI, Sarkkinen, ES, Torpström, J, et al. Long-term effects of four fat-modified diets on blood pressure. J Hum Hypertens. Mar 1994;8(3):209-18. | Intervention/Exposure
2384 | Vafeiadou K, Weech M, Altowaijri H, et al. Replacement of saturated with unsaturated fats had no impact on vascular function but beneficial effects on lipid biomarkers, E-selectin, and blood pressure: results from the randomized, controlled Dietary Intervention and VAScular function (DIVAS) study. Am J Clin Nutr. 2015;102(1):40-48. doi:10.3945/ajcn.114.097089 | Intervention/Exposure
2385 | Vagedes, KM. Changes in diet quality and blood pressure among adolescents with hypertension in response to a dietary intervention emphasizing fruits, vegetables and low-fat dairy products. 2005. | Publication status
2386 | Valsdottir, TD, Øvrebø, B, Falck, TM, et al. Low-carbohydrate high-fat diet and exercise: Effect of a 10-week intervention on body composition and cvd risk factors in overweight and obese women—a randomized controlled trial. Nutrients. Dec 30 2020;13(1)doi:10.3390/nu13010110 | Intervention/Exposure; Sample size/Power
2387 | Valsta, LM, Salminen, I, Aro, A, et al. Alpha-linolenic acid in rapeseed oil partly compensates for the effect of fish restriction on plasma long chain n-3 fatty acids. Eur J Clin Nutr. Apr 1996;50(4):229-35. | Intervention/Exposure
2388 | Vamvakis, A, Gkaliagkousi, E, Lazaridis, A, et al. Impact of intensive lifestyle treatment (Diet plus exercise) on endothelial and vascular function, arterial stiffness and blood pressure in stage 1 hypertension: Results of the hintreat randomized controlled trial. Nutrients. May 7 2020;12(5)doi:10.3390/nu12051326 | Intervention/Exposure
2389 | van Aerde, MA, Soedamah-Muthu, SS, Geleijnse, JM, et al. Dairy intake in relation to cardiovascular disease mortality and all-cause mortality: the Hoorn Study. Eur J Nutr. 2013. 52:609-16. doi:10.1007/s00394-012-0363-z | Intervention/Exposure; Comparator
2390 | van Baak, MA, Larsen, TM, Jebb, SA, et al. Dietary intake of protein from different sources and weight regain, changes in body composition and cardiometabolic risk factors afterweight loss: The DIOgenes study. Nutrients. 2017;9(12):1326. Published 2017 Dec 6. doi:10.3390/nu9121326 | Intervention/Exposure
2391 | Van Beresteijn, EC, van Schaik, M, Schaafsma, G. Milk: does it affect blood pressure? A controlled intervention study. J Intern Med. 1990;228(5):477-482. doi:10.1111/j.1365-2796.1990.tb00266.x | Comparator; Sample size/Power
2392 | van Bussel, BC, Henry, RM, Ferreira, I, et al. A healthy diet is associated with less endothelial dysfunction and less low-grade inflammation over a 7-year period in adults at risk of cardiovascular disease. J Nutr. 2015;145(3):532-540. doi:10.3945/jn.114.201236 | Outcome
2393 | van den Belt, M, van der Haar, S, Oosterink, E, et al. Effect of 4-Week Consumption of Soy Kori-tofu on Cardiometabolic Health Markers: A Double-Blind Randomized Controlled Cross-Over Trial in Adults with Mildly Elevated Cholesterol Levels. Nutrients. Dec 22 2022;15(1)doi:10.3390/nu15010049 | Intervention/Exposure
2394 | van der Gaag, EJ, Wieffer, R, van der Kraats, J. Advising Consumption of Green Vegetables, Beef, and Full-Fat Dairy Products Has No Adverse Effects on the Lipid Profiles in Children. Nutrients. 2017. 9. doi:10.3390/nu9050518 | Intervention/Exposure
2395 | van der Heide JJ, Bilo HJ, Donker JM, Wilmink JM, Tegzess AM. Effect of dietary fish oil on renal function and rejection in cyclosporine-treated recipients of renal transplants. N Engl J Med. 1993;329(11):769-773. doi:10.1056/NEJM199309093291105 | Health status
2396 | van der Made, SM, Berendschot, Ttjm, Kijlstra, A, et al. One-year daily consumption of buttermilk drink containing lutein-enriched egg-yolks does not affect endothelial function in fasting and postprandial state. Sci Rep. 2017. 7:1353. doi:10.1038/s41598-017-01370-7 | Duration
2397 | van der Made, SM, Kelly, ER, Berendschot, TT, et al. Consuming a buttermilk drink containing lutein-enriched egg yolk daily for 1 year increased plasma lutein but did not affect serum lipid or lipoprotein concentrations in adults with early signs of age-related macular degeneration. J Nutr. 2014. 144:1370-7. doi:10.3945/jn.114.195503 | Intervention/Exposure; Comparator
2398 | van der Pols, JC, Gunnell, D, Williams, GM, et al. Childhood dairy and calcium intake and cardiovascular mortality in adulthood: 65-year follow-up of the Boyd Orr cohort. Heart. 2009. 95:1600-6. doi:10.1136/hrt.2009.168716 | Intervention/Exposure; Comparator
2399 | van der Zander, K, Jäkel, M, Bianco, V, et al. Fermented lactotripeptides-containing milk lowers daytime blood pressure in high normal-to-mild hypertensive subjects. Journal of human hypertension. 2008. 22:804-806. doi:10.1038/jhh.2008.59 | Intervention/Exposure; Publication status; Comparator
2400 | van Dijk, SJ, Feskens, EJ, Bos, MB, et al. A saturated fatty acid-rich diet induces an obesity-linked proinflammatory gene expression profile in adipose tissue of subjects at risk of metabolic syndrome. Am J Clin Nutr. 2009;90(6):1656-1664. doi:10.3945/ajcn.2009.27792 | Intervention/Exposure; Sample size/Power
2401 | van Dokkum, W, van der Beek, EJ, de Pee, S, et al. Dutch dietary guidelines: impact on blood lipids, blood pressure, body composition and urinary mineral excretion of Dutch middle-aged men. Eur J Clin Nutr. Sep 1991;45(9):431-9. | Intervention/Exposure; Sample size/Power
2402 | van Hees, AM, Saris, WH, Hul, GB, et al. Effects of dietary fat modification on skeletal muscle fatty acid handling in the metabolic syndrome. Int J Obes (Lond). 2010. 34:859-70. doi:10.1038/ijo.2010.6 | Intervention/Exposure; Sample size/Power
2403 | van het Hof, KH, Weststrate, JA, van den Berg, H, et al. A long-term study on the effect of spontaneous consumption of reduced fat products as part of a normal diet on indicators of health. International Journal of Food Sciences and Nutrition, 48, 19-29. doi:10.3109/09637489709006960 | Intervention/Exposure
2404 | Van Horn, L, Aragaki, AK, Howard, BV, et al. Eating Pattern Response to a Low-Fat Diet Intervention and Cardiovascular Outcomes in Normotensive Women: The Women’s Health Initiative. Curr Dev Nutr. Mar 2020;4(3):nzaa021. doi:10.1093/cdn/nzaa021 | Intervention/Exposure
2405 | Van Horn, L, Liu, K, Gerber, J, et al. Oats and soy in lipid-lowering diets for women with hypercholesterolemia: is there synergy?. J Am Diet Assoc. 2001. 101:1319-25. doi:10.1016/s0002-8223(01)00317-0 | Intervention/Exposure; Comparator
2406 | Van Horn, L, Obarzanek, E, Friedman, LA, et al. Children’s adaptations to a fat-reduced diet: the Dietary Intervention Study in Children (DISC). Pediatrics. 2005. 115:1723-33. doi:10.1542/peds.2004-2392 | Health status; Outcome
2407 | van Meijl, LE, Mensink, RP. Effects of low-fat dairy consumption on markers of low-grade systemic inflammation and endothelial function in overweight and obese subjects: an intervention study. Br J Nutr. 2010. 104:1523-7. doi:10.1017/s0007114510002515 | Outcome
2408 | van Meijl, LE, Mensink, RP. Effects of milk and milk constituents on postprandial lipid and glucose metabolism in overweight and obese men. Br J Nutr. 2013. 110:413-9. doi:10.1017/s0007114512005314 | Duration; Sample size/Power
2409 | van Mierlo, LA, Houben, AJ, van der Knaap, HC, et al. The effect of vitamins and minerals enriched milk on blood pressure in mildly hypertensive subjects. Journal of human hypertension. 2008. 22:54-56. doi:10.1038/sj.jhh.1002256 | Intervention/Exposure
2410 | van Mierlo, LA, Koning, MM, van der Zander, K, et al. Lactotripeptides do not lower ambulatory blood pressure in untreated whites: results from 2 controlled multicenter crossover studies. Am J Clin Nutr. 2009. 89:617-623. doi:10.3945/ajcn.2008.26918 | Intervention/Exposure
2411 | van Nielen, M, Feskens, EJ, Rietman, A, et al. Partly replacing meat protein with soy protein alters insulin resistance and blood lipids in postmenopausal women with abdominal obesity. J Nutr. 2014. 144:1423-9. doi:10.3945/jn.114.193706 | Sample size/Power
2412 | Vanegas, P, Zazpe, I, Santiago, S, et al. Macronutrient quality index and cardiovascular disease risk in the Seguimiento Universidad de Navarra (SUN) cohort. Eur J Nutr. Oct 2022;61(7):3517-3530. doi:10.1007/s00394-022-02901-3 | Intervention/Exposure
2413 | Vanhanen, HT, Blomqvist, S, Ehnholm, C, et al. Serum cholesterol, cholesterol precursors, and plant sterols in hypercholesterolemic subjects with different apoE phenotypes during dietary sitostanol ester treatment. J Lipid Res. 1993. 34:1535-44. | Intervention/Exposure; Health status
2414 | Vanhanen, HT, Miettinen, TA. Effects of unsaturated and saturated dietary plant sterols on their serum contents. Clinica Chimica Acta. Jan 31 1992;205(1-2):97-107. doi:Doi 10.1016/S0009-8981(05)80004-X | Intervention/Exposure
2415 | Varady, KA, Bhutani, S, Klempel, MC, et al. Improvements in vascular health by a low-fat diet, but not a high-fat diet, are mediated by changes in adipocyte biology. Nutr J. 2011. 10:8. doi:10.1186/1475-2891-10-8 | Intervention/Exposure; Sample size/Power
2416 | Varady, KA, Dam, VT, Klempel, MC, et al. Effects of weight loss via high fat vs. low fat alternate day fasting diets on free fatty acid profiles. Sci Rep. 2015. 5:7561. doi:10.1038/srep07561 | Intervention/Exposure; Sample size/Power
2417 | Varenna, M, Binelli, L, Zucchi, F, et al. Unbalanced diet to lower serum cholesterol level is a risk factor for postmenopausal osteoporosis and distal forearm fracture. Osteoporos Int. 2001. 12:296-301. doi:10.1007/s001980170119 | Study design; Intervention/Exposure; Outcome
2418 | Vasilopoulou, D, Markey, O, Kliem, KE, et al. Reformulation initiative for partial replacement of saturated with unsaturated fats in dairy foods attenuates the increase in LDL cholesterol and improves flow-mediated dilatation compared with conventional dairy: the randomized, controlled REplacement of SaturatEd fat in dairy on Total cholesterol (RESET) study. Am J Clin Nutr. 2020. 111:739-748. doi:10.1093/ajcn/nqz344 | Intervention/Exposure; Comparator
2419 | Vásquez-Trespalacios, EM, Romero-Palacio, J. Efficacy of yogurt drink with added plant stanol esters (Benecol®, Colanta) in reducing total and LDL cholesterol in subjects with moderate hypercholesterolemia: a randomized placebo-controlled crossover trial NCT01461798. Lipids Health Dis. 2014. 13:125. doi:10.1186/1476-511x-13-125 | Study design; Intervention/Exposure; Comparator
2420 | Vecka, M, Richterová, B, Zák, A, et al. Changes in serum and adipose tissue fatty acid composition after low calorie diet with respect to dietary fat content in obese. Cas Lek Cesk. 2006;145(6):464-469. | Intervention/Exposure; Publication language
2421 | Vedtofte, MS, Jakobsen, MU, Lauritzen, L, et al. Dietary α-linolenic acid, linoleic acid, and n-3 long-chain PUFA and risk of ischemic heart disease. American Journal of Clinical Nutrition. 2011. 94:1097-1103. doi:10.3945/ajcn.111.018762 | Intervention/Exposure
2422 | Vega-López, S, Ausman, LM, Jalbert, SM, et al. Palm and partially hydrogenated soybean oils adversely alter lipoprotein profiles compared with soybean and canola oils in moderately hyperlipidemic subjects. Am J Clin Nutr. 2006. 84:54-62. doi:10.1093/ajcn/84.1.54 | Sample size/Power
2423 | Vega-López, S, Matthan, NR, Ausman, LM, et al. Substitution of vegetable oil for a partially-hydrogenated fat favorably alters cardiovascular disease risk factors in moderately hypercholesterolemic postmenopausal women. Atherosclerosis. 2009. 207:208-212. doi:10.1016/j.atherosclerosis.2009.03.039 | Intervention/Exposure
2424 | Vela-Vásquez, DA, Sifuentes-Rincón, AM, Delgado-Enciso, I, et al. Effect of Consuming Beef with Varying Fatty Acid Compositions as a Major Source of Protein in Volunteers under a Personalized Nutritional Program. Nutrients. 2022. 14. doi:10.3390/nu14183711 | Comparator; Sample size/Power
2425 | Velázquez-López, L, Santiago-Díaz, G, Nava-Hernández, J, et al. Mediterranean-style diet reduces metabolic syndrome components in obese children and adolescents with obesity. BMC Pediatr. 2014. 14:175. doi:10.1186/1471-2431-14-175 | Intervention/Exposure
2426 | Vélez-Carrasco, W, Lichtenstein, AH, Welty, FK, et al. Dietary restriction of saturated fat and cholesterol decreases HDL ApoA-I secretion. Arterioscler Thromb Vasc Biol. Apr 1999;19(4):918-24. doi:10.1161/01.atv.19.4.918 | Sample size/Power
2427 | Velthuis-te Wierik, EJ, van den Berg, H, Weststrate, JA, et al. Consumption of reduced-fat products: effects on parameters of anti-oxidative capacity. Eur J Clin Nutr. Apr 1996;50(4):214-9. | Intervention/Exposure
2428 | Venkatramanan, S, Joseph, SV, Chouinard, PY, et al. Milk enriched with conjugated linoleic acid fails to alter blood lipids or body composition in moderately overweight, borderline hyperlipidemic individuals. J Am Coll Nutr. Apr 2010;29(2):152-9. doi:10.1080/07315724.2010.10719829 | Comparator; Sample size/Power
2429 | Venø, SK, Schmidt, EB, Jakobsen, MU, et al. Substitution of Linoleic Acid for Other Macronutrients and the Risk of Ischemic Stroke. Stroke. Dec 2017;48(12):3190-3195. doi:10.1161/STROKEAHA.117.017935 | Intervention/Exposure
2430 | Venturini, D, Simão, ANC, Urbano, MR, et al. Effects of extra virgin olive oil and fish oil on lipid profile and oxidative stress in patients with metabolic syndrome. Nutrition. Jun 2015;31(6):834-40. doi:10.1016/j.nut.2014.12.016 | Intervention/Exposure; Comparator
2431 | Verdery, RB, Walford, RL. Changes in plasma lipids and lipoproteins in humans during a 2-year period of dietary restriction in biosphere 2. Arch Intern Med. Apr 27 1998;158(8):900-6. doi:10.1001/archinte.158.8.900 | Intervention/Exposure; Sample size/Power
2432 | Vergnaud, AC, Romaguera, D, Peeters, PH, et al. Adherence to the World Cancer Research Fund/American Institute for Cancer Research guidelines and risk of death in Europe: Results from the European Prospective Investigation into Nutrition and Cancer cohort study1-5. Am J Clin Nutr. 2013;97(5):1107-1120. doi:10.3945/ajcn.112.049569 | Intervention/Exposure
2433 | Veum, VL, Laupsa-Borge, J, Eng, Ø, et al. Visceral adiposity and metabolic syndrome after very high-fat and low-fat isocaloric diets: a randomized controlled trial. American Journal of Clinical Nutrition. Jan 2017;105(1):85-99. doi:10.3945/ajcn.115.123463 | Intervention/Exposure
2434 | Victoria-Montesinos, D, Arcusa, R, García-Muñoz, AM, et al. Effects of the Consumption of Low-Fat Cooked Ham with Reduced Salt Enriched with Antioxidants on the Improvement of Cardiovascular Health: A Randomized Clinical Trial. Nutrients. 2021. 13. doi:10.3390/nu13051480 | Comparator
2435 | Vidon, C, Boucher, P, Cachefo, A, et al. Effects of isoenergetic high-carbohydrate compared with high-fat diets on human cholesterol synthesis and expression of key regulatory genes of cholesterol metabolism. Am J Clin Nutr. May 2001;73(5):878-84. doi:10.1093/ajcn/73.5.878 | Duration; Sample size/Power
2436 | Vijayakumar, V, Shankar, NR, Mavathur, R, et al. Diet enriched with fresh coconut decreases blood glucose levels and body weight in normal adults. J Complement Integr Med. Feb 20 2018;15(3)doi:10.1515/jcim-2017-0097 | Country
2437 | Villamor, E, Marín, C, Mora-Plazas, M, et al. Cooking with soyabean oil increases whole-blood α-linolenic acid in school-aged children: results from a randomized trial. Public Health Nutr. 2015. 18:3420-8. doi:10.1017/s1368980015000762 | Intervention/Exposure; Outcome
2438 | Villareal, DT, Miller Iii, BV, Banks, M, et al. Effect of lifestyle intervention on metabolic coronary heart disease risk factors in obese older adults. American Journal of Clinical Nutrition. 2006. 84:1317-1323. doi:10.1093/ajcn/84.6.1317 | Intervention/Exposure; Sample size/Power
2439 | Villaverde, P, Lajous, M, MacDonald, CJ, et al. Dairy product consumption and hypertension risk in a prospective French cohort of women. Nutr J. 2020. 19:12. doi:10.1186/s12937-020-0527-2 | Comparator
2440 | Vimaleswaran, KS, Zhou, A, Cavadino, A, et al. Evidence for a causal association between milk intake and cardiometabolic disease outcomes using a two-sample Mendelian Randomization analysis in up to 1,904,220 individuals. International Journal of Obesity. 2021. 45:1751-1762. doi:10.1038/s41366-021-00841-2 | Study design; Comparator
2441 | Vincent-Baudry, S, Defoort, C, Gerber, M, et al. The Medi-RIVAGE study: reduction of cardiovascular disease risk factors after a 3-mo intervention with a Mediterranean-type diet or a low-fat diet. Am J Clin Nutr. 2005. 82:964-71. doi:10.1093/ajcn/82.5.964 | Intervention/Exposure
2442 | Violante, B, Gerbaudo, L, Borretta, G, et al. Effects of extra virgin olive oil supplementation at two different low doses on lipid profile in mild hypercholesterolemic subjects: A randomised clinical trial. Journal of Endocrinological Investigation. Nov 2009;32(10):794-796. doi:10.1007/Bf03345747 | Intervention/Exposure; Comparator
2443 | Virtanen, HEK, Koskinen, TT, Voutilainen, S, et al. Intake of different dietary proteins and risk of type 2 diabetes in men: the Kuopio Ischaemic Heart Disease Risk Factor Study. Br J Nutr. 2017. 117:882-893. doi:10.1017/s0007114517000745 | Intervention/Exposure; Outcome
2444 | Virtanen, HEK, Voutilainen, S, Koskinen, TT, et al. Dietary proteins and protein sources and risk of death: the Kuopio Ischaemic Heart Disease Risk Factor Study. Am J Clin Nutr. 2019. 109:1462-1471. doi:10.1093/ajcn/nqz025 | Outcome
2445 | Virtanen, JK, Mursu, J, Tuomainen, TP, et al. Dietary fatty acids and risk of coronary heart disease in men: the Kuopio Ischemic Heart Disease Risk Factor Study. Arterioscler Thromb Vasc Biol. Dec 2014;34(12):2679-87. doi:10.1161/ATVBAHA.114.304082 | Intervention/Exposure
2446 | Viscogliosi, G, Cipriani, E, Liguori, ML, et al. Mediterranean dietary pattern adherence: associations with prediabetes, metabolic syndrome, and related microinflammation. Metab Syndr Relat Disord. 2013. 11:210-6. doi:10.1089/met.2012.0168 | Study design; Outcome
2447 | Visioli, F, Risè, P, Plasmati, E, et al. Very low intakes of N-3 fatty acids incorporated into bovine milk reduce plasma triacylglycerol and increase HDL-cholesterol concentrations in healthy subjects. Pharmacological Research. May 2000;41(5):571-576. doi:DOI 10.1006/phrs.1999.0650 | Sample size/Power
2448 | Vissers LET, Waller M, van der Schouw YT, et al. A pro-inflammatory diet is associated with increased risk of developing hypertension among middle-aged women. Nutr Metab Cardiovasc Dis. 2017;27(6):564-570. doi:10.1016/j.numecd.2017.03.005Nutrition Metabolism and Cardiovascular Diseases. Jun 2017;27(6):564-570. doi:10.1016/j.numecd.2017.03.005 | Intervention/Exposure
2449 | Vissers, LET, Rijksen, J, Boer, JMA, et al. Fatty acids from dairy and meat and their association with risk of coronary heart disease. Eur J Nutr. 2019. 58:2639-2647. doi:10.1007/s00394-018-1811-1 | Intervention/Exposure
2450 | Vissers, LET, Sluijs, I, Burgess, S, et al. Milk intake and incident stroke and CHD in populations of European descent: a Mendelian randomisation study. Br J Nutr. 2022. 128:1789-1797. doi:10.1017/s0007114521004244 | Study design; Comparator
2451 | Vissers, LET, Soedamah-Muthu, SS, van der Schouw, YT, et al. Consumption of a diet high in dairy leads to higher 15:0 in cholesteryl esters of healthy people when compared to diets high in meat and grain. Nutr Metab Cardiovasc Dis. 2020. 30:804-809. doi:10.1016/j.numecd.2020.01.006 | Duration; Sample size/Power
2452 | Vlachopoulos, C, Aznaouridis, K, Alexopoulos, N, et al. Effect of dark chocolate on arterial function in healthy individuals. Am J Hypertens. 2005. 18:785-91. doi:10.1016/j.amjhyper.2004.12.008 | Duration; Sample size/Power
2453 | Voeghtly, LM, Neatrour, DM, Decewicz, DJ, et al. Cardiometabolic risk reduction in an intensive cardiovascular health program. Nutr Metab Cardiovasc Dis. Jul 2013;23(7):662-9. doi:10.1016/j.numecd.2012.01.012 | Intervention/Exposure; Health status
2454 | Vogel, CÉ, Crovesy, L, Rosado, EL, et al. Effect of coconut oil on weight loss and metabolic parameters in men with obesity: a randomized controlled clinical trial. Food Funct. 2020. 11:6588-6594. doi:10.1039/d0fo00872a | Sample size/Power
2455 | Voils, CI, Coffman, CJ, Yancy, WS, et al. A randomized controlled trial to evaluate the effectiveness of CouPLES: a spouse-assisted lifestyle change intervention to improve low-density lipoprotein cholesterol. Prev Med. Jan 2013;56(1):46-52. doi:10.1016/j.ypmed.2012.11.001 | Intervention/Exposure
2456 | Volek, JS, Gómez, AL, Kraemer, WJ. Fasting lipoprotein and postprandial triacylglycerol responses to a low- carbohydrate diet supplemented with n-3 fatty acids. J Am Coll Nutr. Jun 2000;19(3):383-91. doi:10.1080/07315724.2000.10718935 | Sample size/Power
2457 | Volek, JS, Phinney, SD, Forsythe, CE, et al. Carbohydrate restriction has a more favorable impact on the metabolic syndrome than a low fat diet. Lipids. Apr 2009;44(4):297-309. doi:10.1007/s11745-008-3274-2 | Intervention/Exposure
2458 | Vollmer, WM, Sacks, FM, Svetkey, LP. New insights into the effects on blood pressure of diets low in salt and high in fruits and vegetables and low-fat dairy products. Curr Control Trials Cardiovasc Med. 2001. 2:71-74. doi:10.1186/cvm-2-2-071 | Study design
2459 | Volpe, R, Niittynen, L, Korpela, R, et al. Effects of yoghurt enriched with plant sterols on serum lipids in patients with moderate hypercholesterolaemia. Br J Nutr. 2001. 86:233-9. doi:10.1079/bjn2001395 | Intervention/Exposure; Comparator
2460 | von Frankenberg, AD, Marina, A, Song, X, et al. A high-fat, high-saturated fat diet decreases insulin sensitivity without changing intra-abdominal fat in weight-stable overweight and obese adults. Eur J Nutr. 2017;56(1):431-443. doi:10.1007/s00394-015-1108-6 | Intervention/Exposure; Comparator
2461 | von Ruesten, A, Feller, S, Bergmann, MM, et al. Diet and risk of chronic diseases: results from the first 8 years of follow-up in the EPIC-Potsdam study. Eur J Clin Nutr. Apr 2013;67(4):412-9. doi:10.1038/ejcn.2013.7 | Comparator
2462 | Voon, PT, Ng, TK, Lee, VK, et al. Virgin olive oil, palm olein and coconut oil diets do not raise cell adhesion molecules and thrombogenicity indices in healthy Malaysian adults. Eur J Clin Nutr. 2015;69(6):712-716. doi:10.1038/ejcn.2015.26 | Outcome
2463 | Voortman, T, Chen, Z, Girschik, C, et al. Associations between macronutrient intake and coronary heart disease (CHD): The Rotterdam Study. Clin Nutr. 2021. 40:5494-5499. doi:10.1016/j.clnu.2021.08.022 | Intervention/Exposure
2464 | Voortman, T, Kiefte-de Jong, JC, Ikram, MA, et al. Adherence to the 2015 Dutch dietary guidelines and risk of non-communicable diseases and mortality in the Rotterdam Study. Eur J Epidemiol. 2017. 32:993-1005. doi:10.1007/s10654-017-0295-2 | Intervention/Exposure
2465 | Vormund, K, Braun, J, Rohrmann, S, et al. Mediterranean diet and mortality in Switzerland: an alpine paradox?. Eur J Nutr. Feb 2015;54(1):139-48. doi:10.1007/s00394-014-0695-y | Intervention/Exposure; Comparator
2466 | Vorster, HH, Benadé, AJ, Barnard, HC, et al. Egg intake does not change plasma lipoprotein and coagulation profiles. Am J Clin Nutr. 1992;55(2):400-410. doi:10.1093/ajcn/55.2.400 | Intervention/Exposure
2467 | Votruba, SB, Shaw, PA, Oh, EJ, et al. Associations of plasma, RBCs, and hair carbon and nitrogen isotope ratios with fish, meat, and sugar-sweetened beverage intake in a 12-wk inpatient feeding study. American Journal of Clinical Nutrition. 2019. 110:1306-1315. doi:10.1093/ajcn/nqz208 | Outcome
2468 | Vuorio, AF, Gylling, H, Turtola, H, et al. Stanol ester margarine alone and with simvastatin lowers serum cholesterol in families with familial hypercholesterolemia caused by the FH-North Karelia mutation. Arterioscler Thromb Vasc Biol. Feb 2000;20(2):500-6. doi:10.1161/01.atv.20.2.500 | Intervention/Exposure
2469 | Wade, AT, Davis, CR, Dyer, KA, et al. A Mediterranean diet supplemented with dairy foods improves markers of cardiovascular risk: results from the MedDairy randomized controlled trial. American journal of clinical nutrition. 2018. 108:1166-1182. doi:10.1093/ajcn/nqy207 | Intervention/Exposure; Comparator
2470 | Wade, AT, Davis, CR, Dyer, KA, et al. A Mediterranean diet supplemented with dairy foods improves mood and processing speed in an Australian sample: results from the MedDairy randomized controlled trial. Nutr Neurosci. Aug 2020;23(8):646-658. doi:10.1080/1028415X.2018.1543148 | Intervention/Exposure; Outcome
2471 | Wade, AT, Davis, CR, Dyer, KA, et al. A Mediterranean Diet with Fresh, Lean Pork Improves Processing Speed and Mood: Cognitive Findings from the MedPork Randomised Controlled Trial. Nutrients. 2019. 11. doi:10.3390/nu11071521 | Intervention/Exposure; Outcome
2472 | Wade, AT, Davis, CR, Dyer, KA, et al. Effects of Mediterranean diet supplemented with lean pork on blood pressure and markers of cardiovascular risk: findings from the MedPork trial. Br J Nutr. 2019. 122:873-883. doi:10.1017/s0007114519001168 | Intervention/Exposure; Comparator
2473 | Wagemakers, JJ, Prynne, CJ, Stephen, AM, et al. Consumption of red or processed meat does not predict risk factors for coronary heart disease; results from a cohort of British adults in 1989 and 1999. Eur J Clin Nutr. 2009. 63:303-11. doi:10.1038/sj.ejcn.1602954 | Comparator
2474 | Wakai, K, Naito, M, Date, C, et al. Dietary intakes of fat and total mortality among Japanese populations with a low fat intake: the Japan Collaborative Cohort (JACC) Study. Nutr Metab (Lond). 2014. 11:12. doi:10.1186/1743-7075-11-12 | Intervention/Exposure
2475 | Wal, JS, McBurney, MI, Moellering, N, et al. Moderate-carbohydrate low-fat versus low-carbohydrate high-fat meal replacements for weight loss. Int J Food Sci Nutr. Jun 2007;58(4):321-9. doi:10.1080/09637480701240752 | Intervention/Exposure
2476 | Walden, CE, Retzlaff, BM, Buck, BL, et al. Differential effect of National Cholesterol Education Program (NCEP) Step II diet on HDL cholesterol, its subfractions, and apoprotein A-I levels in hypercholesterolemic women and men after 1 year: the beFIT Study. Arterioscler Thromb Vasc Biol. Jun 2000;20(6):1580-7. doi:10.1161/01.atv.20.6.1580 | Intervention/Exposure
2477 | Walden, CE, Retzlaff, BM, Buck, BL, et al. Lipoprotein lipid response to the National Cholesterol Education Program step II diet by hypercholesterolemic and combined hyperlipidemic women and men. Arterioscler Thromb Vasc Biol. Feb 1997;17(2):375-82. doi:10.1161/01.atv.17.2.375 | Intervention/Exposure
2478 | Walker, CG, Loos, RJ, Olson, AD, et al. Genetic predisposition influences plasma lipids of participants on habitual diet, but not the response to reductions in dietary intake of saturated fatty acids. Atherosclerosis. 2011. 215:421-7. doi:10.1016/j.atherosclerosis.2010.12.039 | Intervention/Exposure
2479 | Walker, KZ, O’Dea, K, Johnson, L, et al. Body fat distribution and non-insulindependent diabetes: comparison of a fiber-rich, high-carbohydrate, low-fat (23%) diet and a 35% fat diet high in monounsaturated fat. Nutr Metab Cardiovasc Dis. Aug 1999;9(4):176-83. | Intervention/Exposure; Health status
2480 | Wallace, AJ, Humphries, SE, Fisher, RM, et al. Genetic factors associated with response of LDL subfractions to change in the nature of dietary fat. Atherosclerosis. 2000. 149:387-94. doi:10.1016/s0021-9150(99)00328-7 | Intervention/Exposure
2481 | Wallace, AJ, Mann, JI, Sutherland, WH, et al. Variation in plasma cholesterol response to dietary change. Nutr Metab Cardiovasc Dis. Aug 1999;9(4):176-83. | Intervention/Exposure
2482 | Wallström, P, Sonestedt, E, Hlebowicz, J, et al. Dietary fiber and saturated fat intake associations with cardiovascular disease differ by sex in the Malmö Diet and Cancer Cohort: a prospective study. PLoS One. 2012. 7:e31637. doi:10.1371/journal.pone.0031637 | Intervention/Exposure
2483 | Wan, CJ, Lin, LY, Yu, TH, et al. Metabolic syndrome associated with habitual indulgence and dietary behavior in middle-aged health-care professionals. J Diabetes Investig. Dec 3 2010;1(6):259-65. doi:10.1111/j.2040-1124.2010.00055.x | Study design; Intervention/Exposure
2484 | Wan, Y, Vinson, JA, Etherton, TD, et al. Effects of cocoa powder and dark chocolate on LDL oxidative susceptibility and prostaglandin concentrations in humans. Am J Clin Nutr. Nov 2001;74(5):596-602. doi:10.1093/ajcn/74.5.596 | Sample size/Power
2485 | Wang RZ, Zhang WS, Jiang CQ, Zhu F, Jin YL, Xu L. Association of fish and meat consumption with non-alcoholic fatty liver disease: Guangzhou Biobank Cohort Study. BMC Public Health. 2023;23(1):2433. doi:10.1186/s12889-023-17398-6 | Study design
2486 | Wang, C, Yatsuya, H, Lin, Y, et al. Milk Intake and Stroke Mortality in the Japan Collaborative Cohort Study-A Bayesian Survival Analysis. Nutrients. 2020. 12. doi:10.3390/nu12092743 | Intervention/Exposure; Comparator
2487 | Wang, C, Yatsuya, H, Tamakoshi, K, et al. Milk drinking and mortality: findings from the Japan collaborative cohort study. J Epidemiol. 2015. 25:66-73. doi:10.2188/jea.JE20140081 | Intervention/Exposure; Comparator
2488 | Wang, D, Campos, H, Baylin, A. Red meat intake is positively associated with non-fatal acute myocardial infarction in the Costa Rica Heart Study. British Journal of Nutrition. Aug 2017;118(4):303-311. doi:10.1017/S000711451700201x | Study design
2489 | Wang, D, Karvonen-Gutierrez, CA, Jackson, EA, et al. Western Dietary Pattern Derived by Multiple Statistical Methods Is Prospectively Associated with Subclinical Carotid Atherosclerosis in Midlife Women. J Nutr. 2020. 150:579-591. doi:10.1093/jn/nxz270 | Intervention/Exposure
2490 | Wang, DD, Li, Y, Chiuve, SE, et al. Association of Specific Dietary Fats With Total and Cause-Specific Mortality. JAMA Intern Med. 2016. 176:1134-45. doi:10.1001/jamainternmed.2016.2417 | Intervention/Exposure
2491 | Wang, H, Fox, CS, Troy, LM, et al. Longitudinal association of dairy consumption with the changes in blood pressure and the risk of incident hypertension: the Framingham Heart Study. Br J Nutr. 2015. 114:1887-99. doi:10.1017/s0007114515003578 | Comparator
2492 | Wang, H, Wang, Y, Shi, Z, et al. Association between Dietary Patterns and Metabolic Syndrome and Modification Effect of Altitude: A Cohort Study of Tibetan Adults in China. Nutrients. 2023. 15. doi:10.3390/nu15092226 | Intervention/Exposure
2493 | Wang, K, Xiang, Q, Hu, L, et al. Frequency of Egg Intake Associated with Mortality in Chinese Adults: An 8-Year Nationwide Cohort Study. Int J Environ Res Public Health. 2022. 19. doi:10.3390/ijerph192214777 | Intervention/Exposure; Outcome
2494 | Wang, L, Manson, JE, Buring, JE, et al. Dietary intake of dairy products, calcium, and vitamin D and the risk of hypertension in middle-aged and older women. Hypertension. Apr 2008;51(4):1073-9. doi:10.1161/HYPERTENSIONAHA.107.107821 | Comparator
2495 | Wang, L, Manson, JE, Buring, JE, et al. Meat intake and the risk of hypertension in middle-aged and older women. J Hypertens. Feb 2008;26(2):215-22. doi:10.1097/HJH.0b013e3282f283dc | Comparator
2496 | Wang, L, Manson, JE, Forman, JP, et al. Dietary fatty acids and the risk of hypertension in middle-aged and older women. Hypertension. Oct 2010;56(4):598-604. doi:10.1161/HYPERTENSIONAHA.110.154187 | Intervention/Exposure
2497 | Wang, L, Tao, L, Hao, L, et al. A Moderate-Fat Diet with One Avocado per Day Increases Plasma Antioxidants and Decreases the Oxidation of Small, Dense LDL in Adults with Overweight and Obesity: A Randomized Controlled Trial. J Nutr. 2020. 150:276-284. doi:10.1093/jn/nxz231 | Intervention/Exposure
2498 | Wang, M, Wang, Z, Lee, Y, et al. Dietary Meat, Trimethylamine N-Oxide-Related Metabolites, and Incident Cardiovascular Disease Among Older Adults: The Cardiovascular Health Study. Arterioscler Thromb Vasc Biol. 2022. 42:e273-e288. doi:10.1161/atvbaha.121.316533 | Comparator
2499 | Wang, WQ, Wei, B, Song, YP, et al. Metabolically healthy obesity and unhealthy normal weight rural adults in Xinjiang: prevalence and the associated factors. BMC Public Health. Oct 26 2021;21(1):1940. doi:10.1186/s12889-021-11996-y | Study design
2500 | Wang, X, Yu, C, Lv, J, et al. Consumption of soy products and cardiovascular mortality in people with and without cardiovascular disease: a prospective cohort study of 0.5 million individuals. European Journal of Nutrition. Dec 2021;60(8):4429-4438. doi:10.1007/s00394-021-02602-3 | Intervention/Exposure
2501 | Wang, XJ, Jiang, CQ, Zhang, WS, et al. Milk consumption and risk of mortality from all-cause, cardiovascular disease and cancer in older people. Clin Nutr. 2020. 39:3442-3451. doi:10.1016/j.clnu.2020.03.003 | Intervention/Exposure; Comparator
2502 | Wang, XY, Liu, FC, Yang, XL, et al. Association of cardiovascular diseases with milk intake among general Chinese adults. Chin Med J (Engl). 2020. 133:1144-1154. doi:10.1097/cm9.0000000000000786 | Country
2503 | Wang, Y, Clark, C, Cross, TW, et al. Effects of Adding Lean Red Meat to A Vegetarian Diet on Gut Microbiota in Young Adults: a Randomized Controlled Trial. J Nutr. May 2023;153(5):1439-1452. doi:10.1016/j.tjnut.2023.03.013 | Study design; Publication status
2504 | Wang, Y, Lindemann, SR, Cross, TL, et al. Effects of Adding Lean Red Meat to a U.S.-Style Healthy Vegetarian Dietary Pattern on Gut Microbiota and Cardiovascular Risk Factors in Young Adults: a Crossover Randomized Controlled Trial. J Nutr. 2023. 153:1439-1452. doi:10.1016/j.tjnut.2023.03.013 | Duration; Sample size/Power
2505 | Wang, Y, Su, X, Chen, Y, et al. Unfavorable Dietary Quality Contributes to Elevated Risk of Ischemic Stroke among Residents in Southwest China: Based on the Chinese Diet Balance Index 2016 (DBI-16). Nutrients. 2022. 14. doi:10.3390/nu14030694 | Comparator
2506 | Wang, YF, Yancy, WS, Jr, Yu, et al. The relationship between dietary protein intake and blood pressure: results from the PREMIER study. J Hum Hypertens. 2008. 22:745-54. doi:10.1038/jhh.2008.64 | Comparator
2507 | Wang, Z, Huang, Q, Wang, L, et al. Moderate Intake of Lean Red Meat was Associated with Lower Risk of Elevated Blood Pressure in Chinese Women: Results from the China Health and Nutrition Survey, 1991-2015. Nutrients. 2020. 12. doi:10.3390/nu12051369 | Comparator
2508 | Wardlaw, GM, Snook, JT, Lin, MC, et al. Serum lipid and apolipoprotein concentrations in healthy men on diets enriched in either canola oil or safflower oil. Am J Clin Nutr. 1991;54(1):104-110. doi:10.1093/ajcn/54.1.104 | Intervention/Exposure; Sample size/Power
2509 | Wardlaw, GM, Snook, JT, Park, S, et al. Relative effects on serum lipids and apolipoproteins of a caprenin-rich diet compared with diets rich in palm oil/palm-kernel oil or butter. Am J Clin Nutr. Mar 1995;61(3):535-42. doi:10.1093/ajcn/61.3.535 | Intervention/Exposure; Sample size/Power
2510 | Wardlaw, GM, Snook, JT. Effect of diets high in butter, corn oil, or high-oleic acid sunflower oil on serum lipids and apolipoproteins in men. Am J Clin Nutr. May 1990;51(5):815-21. doi:10.1093/ajcn/51.5.815 | Intervention/Exposure; Sample size/Power
2511 | Wardle, J, Rogers, P, Judd, P, et al. Randomized trial of the effects of cholesterol-lowering dietary treatment on psychological function. Am J Med. 2000. 108:547-53. doi:10.1016/s0002-9343(00)00330-2 | Intervention/Exposure
2512 | Warensjö, E, Jansson, JH, Berglund, L, et al. Estimated intake of milk fat is negatively associated with cardiovascular risk factors and does not increase the risk of a first acute myocardial infarction. A prospective case-control study. Br J Nutr. 2004. 91:635-42. doi:10.1079/bjn20041080 | Study design; Intervention/Exposure
2513 | Warensjö, E, Jansson, JH, Cederholm, T, et al. Biomarkers of milk fat and the risk of myocardial infarction in men and women: a prospective, matched case-control study. Am J Clin Nutr. 2010. 92:194-202. doi:10.3945/ajcn.2009.29054 | Intervention/Exposure; Comparator
2514 | Warensjö, E, Smedman, A, Stegmayr, B, et al. Stroke and plasma markers of milk fat intake-a prospective nested case-control study. Nutr J. 2009. 8:21. doi:10.1186/1475-2891-8-21 | Intervention/Exposure
2515 | Warensjö, E, Sundström, J, Lind, L, et al. Factor analysis of fatty acids in serum lipids as a measure of dietary fat quality in relation to the metabolic syndrome in men. Am J Clin Nutr. 2006;84(2):442-448. doi:10.1093/ajcn/84.1.442 | Outcome
2516 | Warensjö, E, Sundström, J, Vessby, B, et al. Markers of dietary fat quality and fatty acid desaturation as predictors of total and cardiovascular mortality: a population-based prospective study. Am J Clin Nutr. 2008. 88:203-9. doi:10.1093/ajcn/88.1.203 | Intervention/Exposure
2517 | Watts, GF, Jackson, P, Mandalia, S, et al. Nutrient intake and progression of coronary artery disease. Am J Cardiol. Feb 15 1994;73(5):328-32. doi:10.1016/0002-9149(94)90003-5 | Intervention/Exposure; Sample size/Power
2518 | Weech, M, Altowaijri, H, Mayneris-Perxachs, J, et al. Replacement of dietary saturated fat with unsaturated fats increases numbers of circulating endothelial progenitor cells and decreases numbers of microparticles: findings from the randomized, controlled Dietary Intervention and VAScular function (DIVAS) study. Am J Clin Nutr. Jun 1 2018;107(6):876-882. doi:10.1093/ajcn/nqy018 | Outcome
2519 | Weech, M, Vafeiadou, K, Hasaj, M, et al. Development of a food-exchange model to replace saturated fat with MUFAs and n-6 PUFAs in adults at moderate cardiovascular risk. Journal of Nutrition. Jun 2014;144(6):846-855. doi:10.3945/jn.114.190645 | Study design; Intervention/Exposure
2520 | Weggemans, RM, Zock, PL, Urgert, R, et al. Differences between men and women in the response of serum cholesterol to dietary changes. European Journal of Clinical Investigation. Oct 1999;29(10):827-834. | Study design; Intervention/Exposure
2521 | Weghuber, D, Widhalm, K. Effect of 3-month treatment of children and adolescents with familial and polygenic hypercholesterolaemia with a soya-substituted diet. Br J Nutr. 2008. 99:281-6. doi:10.1017/s0007114507807999 | Health status; Sample size/Power
2522 | Wei, L, Fan, J, Dong, R, et al. The Effect of Dietary Pattern on Metabolic Syndrome in a Suburban Population in Shanghai, China. Nutrients. 2023. 15. doi:10.3390/nu15092185 | Study design; Intervention/Exposure
2523 | Weill, P, Schmitt, B, Chesneau, G, et al. Effects of introducing linseed in livestock diet on blood fatty acid composition of consumers of animal products. Ann Nutr Metab. 2002;46(5):182-91. doi:10.1159/000065405 | Intervention/Exposure
2524 | Wells, AS, Read, NW, Laugharne, JD, et al. Alterations in mood after changing to a low-fat diet. Br J Nutr. Jan 1998;79(1):23-30. doi:10.1079/bjn19980005 | Intervention/Exposure; Sample size/Power
2525 | Welty, FK, Nasca, MM, Lew, NS, et al. Effect of onsite dietitian counseling on weight loss and lipid levels in an outpatient physician office. Am J Cardiol. 2007. 100:73-5. doi:10.1016/j.amjcard.2007.02.056 | Intervention/Exposure
2526 | Welty, FK, Stuart, E, O’Meara, M, et al. Effect of addition of exercise to therapeutic lifestyle changes diet in enabling women and men with coronary heart disease to reach Adult Treatment Panel III low-density lipoprotein cholesterol goal without lowering high-density lipoprotein cholesterol. American Journal of Cardiology. May 15 2002;89(10):1201-+. doi:Pii S0002-9149(02)02305-6 | Intervention/Exposure; Health status
2527 | Wen Hua, Ling, Laitinen, M, Hanninen, O. Shifting from conventional diet to an uncooked vegan diet reversibly alters serum lipid and apolipoprotein levels. Nutrition Research. 1992. 12: 1431-40. doi:10.1016/S0271-5317(05)80185-X | Sample size/Power
2528 | Weng, LC, Steffen, LM, Szklo, M, et al. A diet pattern with more dairy and nuts, but less meat is related to lower risk of developing hypertension in middle-aged adults: the Atherosclerosis Risk in Communities (ARIC) study. Nutrients. 2013. 5:1719-33. doi:10.3390/nu5051719 | Intervention/Exposure; Comparator
2529 | Wennersberg, MH, Smedman, A, Turpeinen, AM, et al. Dairy products and metabolic effects in overweight men and women: results from a 6-mo intervention study. American journal of clinical nutrition. 2009. 90:960-968. doi:10.3945/ajcn.2009.27664 | Comparator
2530 | Werner, LB, Hellgren, LI, Raff, M, et al. Effects of butter from mountain-pasture grazing cows on risk markers of the metabolic syndrome compared with conventional Danish butter: a randomized controlled study. Lipids Health Dis. Jul 10 2013;12:99. doi:10.1186/1476-511X-12-99 | Sample size/Power
2531 | Wernicke, C, Pohrt, A, Pletsch-Borba, L, et al. Effect of unsaturated fat and protein intake on liver fat in people at risk of unhealthy aging: 1-year results of a randomized controlled trial. American Journal of Clinical Nutrition. Apr 2023;117(4):785-793. doi:10.1016/j.ajcnut.2023.01.010 | Intervention/Exposure
2532 | West, SG, Gebauer, SK, Kay, CD, et al. Diets containing pistachios reduce systolic blood pressure and peripheral vascular responses to stress in adults with dyslipidemia. Hypertension. 2012. 60:58-63. doi:10.1161/hypertensionaha.111.182147 | Intervention/Exposure
2533 | West, SG, Krick, AL, Klein, LC, et al. Effects of diets high in walnuts and flax oil on hemodynamic responses to stress and vascular endothelial function. Journal of the American College of Nutrition. 2010. 29:595-603. doi:10.1080/07315724.2010.10719898 | Intervention/Exposure
2534 | West, SG, McIntyre, MD, Piotrowski, MJ, et al. Effects of dark chocolate and cocoa consumption on endothelial function and arterial stiffness in overweight adults. Br J Nutr. 2014. 111:653-61. doi:10.1017/s0007114513002912 | Intervention/Exposure; Comparator
2535 | Westman, EC, Yancy, WS, Jr, Olsen, et al. Effect of a low-carbohydrate, ketogenic diet program compared to a low-fat diet on fasting lipoprotein subclasses. Int J Cardiol. 2006. 110:212-6. doi:10.1016/j.ijcard.2005.08.034 | Intervention/Exposure
2536 | Weston, LJ, Kim, H, Talegawkar, SA, et al. Plant-based diets and incident cardiovascular disease and all-cause mortality in African Americans: A cohort study. PLoS Med. Jan 2022;19(1):e1003863. doi:10.1371/journal.pmed.1003863 | Comparator
2537 | Weststrate, JA, Meijer, GW. Plant sterol-enriched margarines and reduction of plasma total- and LDL-cholesterol concentrations in normocholesterolaemic and mildly hypercholesterolaemic subjects. Eur J Clin Nutr. 1998. 52:334-43. doi:10.1038/sj.ejcn.1600559 | Intervention/Exposure; Duration
2538 | Weststrate, JA, van het Hof, KH, van den Berg, H, et al. A comparison of the effect of free access to reduced fat products or their full fat equivalents on food intake, body weight, blood lipids and fat-soluble antioxidants levels and haemostasis variables. European Journal of Clinical Nutrition. Jun 1998;52(6):389-395. doi:DOI 10.1038/sj.ejcn.1600570 | Intervention/Exposure
2539 | White, E, Shattuck, AL, Kristal, AR, et al. Maintenance of a low-fat diet: follow-up of the Women’s Health Trial. Cancer Epidemiol Biomarkers Prev. May-Jun 1992;1(4):315-23. | Intervention/Exposure
2540 | Widhalm, HK, Herkner, K, Kiefer, I, et al. Effect of daily intake of yoghurt and bread enriched with biologically active substances on blood lipids and vitamin A in adolescents and young adults. Int J Food Sci Nutr. Feb 2011;62(1):52-9. doi:10.3109/09637486.2010.507186 | Intervention/Exposure
2541 | Widhalm, K, Brazda, G, Schneider, B, et al. Effect of soy protein diet versus standard low fat, low cholesterol diet on lipid and lipoprotein levels in children with familial or polygenic hypercholesterolemia. J Pediatr. 1993. 123:30-4. doi:10.1016/s0022-3476(05)81533-1 | Intervention/Exposure; Comparator; Sample size/Power
2542 | Willett, WC, Stampfer, MJ, Manson, JE, et al. Intake of trans fatty acids and risk of coronary heart disease among women. Lancet. Mar 6 1993;341(8845):581-585. doi:Doi 10.1016/0140-6736(93)90350-P | Intervention/Exposure
2543 | Willett, WC. Will it be cheese, bologna, or peanut butter?. European Journal of Epidemiology. Apr 2017;32(4):257-259. doi:10.1007/s10654-017-0257-8 | Study design
2544 | Williams, CL, Strobino, BA. Childhood diet, overweight, and CVD risk factors: The healthy start project. Prev Cardiol. Winter 2008;11(1):11-20. doi:10.1111/j.1520-037x.2007.06677.x | Intervention/Exposure
2545 | Williams, KA, Fughhi, I, Fugar, S, et al. Nutrition Intervention for Reduction of Cardiovascular Risk in African Americans Using the 2019 American College of Cardiology/American Heart Association Primary Prevention Guidelines. Nutrients. 2021. 13. doi:10.3390/nu13103422 | Intervention/Exposure
2546 | Williams, PT, Blanche, PJ, Rawlings, R, et al. Concordant lipoprotein and weight responses to dietary fat change in identical twins with divergent exercise levels 1. Am J Clin Nutr. 2005. 82:181-7. doi:10.1093/ajcn.82.1.181 | Intervention/Exposure
2547 | Williams, PT. Interactive effects of exercise, alcohol, and vegetarian diet on coronary artery disease risk factors in 9242 runners: the National Runners’ Health Study. Am J Clin Nutr. Nov 1997;66(5):1197-206. doi:10.1093/ajcn/66.5.1197 | Study design; Intervention/Exposure
2548 | Winkvist, A, Klingberg, S, Nilsson, LM, et al. Longitudinal 10-year changes in dietary intake and associations with cardio-metabolic risk factors in the Northern Sweden Health and Disease Study. Nutr J. 2017. 16:20. doi:10.1186/s12937-017-0241-x | Intervention/Exposure
2549 | Wirth, J, di Giuseppe, R, Boeing, H, et al. A Mediterranean-style diet, its components and the risk of heart failure: a prospective population-based study in a non-Mediterranean country. Eur J Clin Nutr. 2016. 70:1015-21. doi:10.1038/ejcn.2016.140 | Intervention/Exposure; Comparator
2550 | Witschi, JC, Capper, AL, Ellison, RC. Sources of fat, fatty acids, and cholesterol in the diets of adolescents. J Am Diet Assoc. Oct 1990;90(10):1429-31. | Study design; Intervention/Exposure; Outcome
2551 | Wofford, MR, Rebholz, CM, Reynolds, K, et al. Effect of soy and milk protein supplementation on serum lipid levels: a randomized controlled trial. Eur J Clin Nutr. 2012. 66:419-25. doi:10.1038/ejcn.2011.168 | Intervention/Exposure; Comparator
2552 | Wolfe, BM, Giovannetti, PM. Short-term effects of substituting protein for carbohydrate in the diets of moderately hypercholesterolemic human subjects. Metabolism. 1991. 40:338-43. doi:10.1016/0026-0495(91)90142-j | Intervention/Exposure; Sample size/Power
2553 | Wolfe, BM, Piché, LA. Replacement of carbohydrate by protein in a conventional-fat diet reduces cholesterol and triglyceride concentrations in healthy normolipidemic subjects. Clin Invest Med. Aug 1999;22(4):140-8. | Sample size/Power
2554 | Wolfs, M, de Jong, N, Ocké, MC, et al. Effectiveness of customary use of phytosterol/-stanol enriched margarines on blood cholesterol lowering. Food Chem Toxicol. 2006. 44:1682-8. doi:10.1016/j.fct.2006.05.006 | Intervention/Exposure
2555 | Wolmarans, P, Benadé, AJ, Kotze, TJ, et al. Plasma lipoprotein response to substituting fish for red meat in the diet. Am J Clin Nutr. May 1991;53(5):1171-6. doi:10.1093/ajcn/53.5.1171 | Sample size/Power
2556 | Wolmarans, P, Labadarios, D, Benadé, AJ, et al. The influence of consuming fatty fish instead of red meat on plasma levels of vitamins A, C and E. Eur J Clin Nutr. Feb 1993;47(2):97-103. | Sample size/Power
2557 | Wolmarans, P, Laubscher, JA, van der Merwe, S, et al. Effects of a prudent diet containing either lean beef and mutton or fish and skinless chicken on the plasma lipoproteins and fatty acid composition of triacylglycerol and cholesteryl ester of hypercholesterolemic subjects. J Nutr Biochem. 1999. 10:598-608. doi:10.1016/s0955-2863(99)00048-0 | Sample size/Power
2558 | Wong, VCH, Maguire, JL, Omand, JA, et al. A Positive Association Between Dietary Intake of Higher Cow’s Milk-Fat Percentage and Non-High-Density Lipoprotein Cholesterol in Young Children. J Pediatr. 2019. 211:105-111.e2. doi:10.1016/j.jpeds.2019.03.047 | Comparator
2559 | Woo, J, Leung, SS, Ho, SC, et al. Dietary practices and lipid intake in relation to plasma lipid profile in Hong Kong Chinese. Eur J Clin Nutr. 1997. 51:467-71. doi:10.1038/sj.ejcn.1600430 | Study design; Intervention/Exposure
2560 | Wood, AD. Patterns of dietary intake and serum carotenoid and tocopherol status are associated with biomarkers of chronic low-grade systemic inflammation and cardiovascular risk. Br J Nutr. Oct 28 2014;112(8):1341-52. doi:10.1017/S0007114514001962 | Intervention/Exposure
2561 | Wood, PD, Stefanick, ML, Williams, PT, et al. The effects on plasma lipoproteins of a prudent weight-reducing diet, with or without exercise, in overweight men and women. New England Journal of Medicine. Aug 15 1991;325(7):461-466. doi:Doi 10.1056/Nejm199108153250703 | Intervention/Exposure; Comparator
2562 | Wu, F, Zhuang, P, Zhan, C, et al. Egg and Dietary Cholesterol Consumption and the Prevalence of Metabolic Syndrome: Findings from a Population-Based Nationwide Cohort. Journal of the Academy of Nutrition and Dietetics. 2022. 122:758-770. doi:10.1016/j.jand.2021.09.010 | Study design
2563 | Wu, JH, Lemaitre, RN, Imamura, F, et al. Fatty acids in the de novo lipogenesis pathway and risk of coronary heart disease: the Cardiovascular Health Study. Am J Clin Nutr. 2011. 94:431-8. doi:10.3945/ajcn.111.012054 | Intervention/Exposure
2564 | Wu, K, Bowman, R, Welch, AA, et al. Apolipoprotein E polymorphisms, dietary fat and fibre, and serum lipids: the EPIC Norfolk study. Eur Heart J. Dec 2007;28(23):2930-6. doi:10.1093/eurheartj/ehm482 | Intervention/Exposure
2565 | Wu, MY, Du, MH, Wen, H, et al. Effects of n-6 PUFA-rich soybean oil, MUFA-rich olive oil and camellia seed oil on weight and cardiometabolic profiles among Chinese women: a 3-month double-blind randomized controlled-feeding trial. Food Funct. 2022. 13:4375-4383. doi:10.1039/d1fo03759e | Intervention/Exposure
2566 | Wu, X, Roussell, MA, Hill, AM, et al. Baseline Insulin Resistance Is a Determinant of the Small, Dense Low-Density Lipoprotein Response to Diets Differing in Saturated Fat, Protein, and Carbohydrate Contents. Nutrients. 2021. 13. doi:10.3390/nu13124328 | Sample size/Power
2567 | Wycherley, TP, Brinkworth, GD, Keogh, JB, et al. Long-term effects of weight loss with a very low carbohydrate and low fat diet on vascular function in overweight and obese patients. Journal of Internal Medicine. May 2010;267(5):452-461. doi:10.1111/j.1365-2796.2009.02174.x | Intervention/Exposure
2568 | Xia, H, Zhou, Y, Wang, Y, et al. The Association of Dietary Pattern with the Risk of Prehypertension and Hypertension in Jiangsu Province: A Longitudinal Study from 2007 to 2014. Int J Environ Res Public Health. 2022. 19. doi:10.3390/ijerph19137620 | Intervention/Exposure
2569 | Xia, Y, Gu, Y, Yu, F, et al. Association between dietary patterns and metabolic syndrome in Chinese adults: a propensity score-matched case-control study. Scientific reports. 2016. 6:34748. doi:10.1038/srep34748 | Study design
2570 | Xiao, X, Qin, Z, Lv, X, et al. Dietary patterns and cardiometabolic risks in diverse less-developed ethnic minority regions: results from the China Multi-Ethnic Cohort (CMEC) Study. Lancet Reg Health West Pac. 2021. 15:100252. doi:10.1016/j.lanwpc.2021.100252 | Study design
2571 | Xiao, Y, Zhang, ZT, Wang, JB, et al. Effects of dietary intervention on hyperlipidemia in eight communities of Beijing, China. Biomed Environ Sci. Jun 2003;16(2):112-8. | Intervention/Exposure; Country
2572 | Xing, M, Chen, Z, Cui, L, et al. Yogurt and green tea regimen in the preventions of heart disease and cancer in men. Eur J Prev Cardiol. 2019. 26:Np3-np4. doi:10.1177/2047487318800769 | Study design; Publication status
2573 | Xu, J, Eilat-Adar, S, Loria, C, et al. Dietary fat intake and risk of coronary heart disease: the Strong Heart Study. Am J Clin Nutr. 2006. 84:894-902. doi:10.1093/ajcn/84.4.894 | Intervention/Exposure
2574 | Xu, M, Ng, SS, Bray, GA, et al. Dietary Fat Intake Modifies the Effect of a Common Variant in the LIPC Gene on Changes in Serum Lipid Concentrations during a LongTerm Weight-Loss Intervention Trial. J Nutr. Jun 2015;145(6):1289-94. doi:10.3945/jn.115.212514 | Intervention/Exposure
2575 | Xu, X, Byles, J, Shi, Z, et al. Dietary pattern transitions, and the associations with BMI, waist circumference, weight and hypertension in a 7-year follow-up among the older Chinese population: a longitudinal study. BMC Public Health. 2016. 16:743. doi:10.1186/s12889-016-3425-y | Intervention/Exposure; Country
2576 | Xu, X, Byles, JE, Shi, Z, et al. Dietary patterns, dietary lead exposure and hypertension in the older Chinese population. Asia Pac J Clin Nutr. 2018. 27:451-459. doi:10.6133/apjcn.032017.20 | Study design
2577 | Xu, X, Kabir, A, Barr, ML, et al. Different Types of Long-Term Milk Consumption and Mortality in Adults with Cardiovascular Disease: A Population-Based Study in 7236 Australian Adults over 8.4 Years. Nutrients. 2022. 14. doi:10.3390/nu14030704 | Health status; Outcome
2578 | Y Fang, J Xia, Y Lian, M Zhang, Y Kang, Z Zhao, et al. The burden of cardiovascular disease attributable to dietary risk factors in the provinces of China, 2002-2018: a nationwide population-based study.. The Lancet regional health. Western Pacific. 2023. 37:100784. doi:10.1016/j.lanwpc.2023.100784 | Intervention/Exposure; Comparator
2579 | Y Jeong, KW Lee, H Kim, Y Kim. Association of milk and dairy product consumption with the incidence of cardio-cerebrovascular disease incidence in middle-aged and older Korean adults: a 16-year follow-up of the Korean Genome and Epidemiology Study.. Nutrition research and practice. 2023. 17:1225-1237. doi:10.4162/nrp.2023.17.6.1225 | Comparator
2580 | Y Li, Y Yang, L Ju, W Piao, X Wei, L Zhao, et al. Association of the Protective Dietary Pattern for Blood Pressure with Elevated Blood Pressure and Hypertension among Chinese Children and Adolescents Aged 6-17 Years Old: Data from China Nutrition and Health Surveillance (2015-2017). Nutrients. 2023. 15. doi:10.3390/nu15234927 | Study design; Intervention/Exposure
2581 | Y Xie, H Chen, J Xu, P Qu, L Zhu, Y Tan, et al. Cheese consumption on atherosclerosis, atherosclerotic cardiovascular diseases and its complications: A twosample Mendelian randomization study. Nutr Metab Cardiovasc Dis. Mar 2024;34(3):691-698. doi:10.1016/j.numecd.2023.11.008 | Intervention/Exposure
2582 | Yae, JH, Oh, YK, Joo, BK, et al. Plant stanol esters in low-fat yogurt reduces total and low-density lipoprotein cholesterol and low-density lipoprotein oxidation in normocholesterolemic and mildly hypercholesterolemic subjects. Nutrition Research. 2005. 25(8):743-753. doi: http://dx.doi.org/10.1016/j.nutres.2005.08.004 | Intervention/Exposure; Comparator
2583 | Yahay, M, Heidari, Z, Allameh, Z, et al. The effects of canola and olive oils consumption compared to sunflower oil, on lipid profile and hepatic steatosis in women with polycystic ovarian syndrome: a randomized controlled trial. Lipids Health Dis. 2021. 20:7. doi:10.1186/s12944-021-01433-9 | Intervention/Exposure
2584 | Yakoob, MY, Shi, P, Hu, FB, et al. Circulating biomarkers of dairy fat and risk of incident stroke in U.S. men and women in 2 large prospective cohorts. Am J Clin Nutr. Dec 2014;100(6):1437-47. doi:10.3945/ajcn.114.083097 | Intervention/Exposure
2585 | Yamagishi, K, Iso, H, Kokubo, Y, et al. Dietary intake of saturated fatty acids and incident stroke and coronary heart disease in Japanese communities: the JPHC Study. Am J Clin Nutr. Oct 2010;92(4):759-65. doi:10.3945/ajcn.2009.29146 | Intervention/Exposure
2586 | Yamagishi, K, Iso, H, Yatsuya, H, et al. Dietary intake of saturated fatty acids and mortality from cardiovascular disease in Japanese: the Japan Collaborative Cohort Study for Evaluation of Cancer Risk (JACC) Study. Am J Clin Nutr. 2010. 92:759-65. doi:10.3945/ajcn.2009.29146 | Study design; Intervention/Exposure
2587 | Yamashita, T, Sasahara, T, Pomeroy, SE, et al. Arterial compliance, blood pressure, plasma leptin, and plasma lipids in women are improved with weight reduction equally with a meat-based diet and a plant-based diet. Metabolism. 1998. 47:1308-14. doi:10.1016/s0026-0495(98)90297-9 | Sample size/Power
2588 | Yamori, Y, Nara, Y, Mizushima, S, et al. Nutritional factors for stroke and major cardiovascular diseases: international epidemiological comparison of dietary prevention. Health Rep. 1994;6(1):22-7. | Intervention/Exposure
2589 | Yang, H, Kim, H, Kim, JM, et al. Associations of dietary intake and metabolic syndrome risk parameters in Vietnamese female marriage immigrants in South Korea: The KoGES follow-up study. Nutr Res Pract. 2016. 10:313-20. doi:10.4162/nrp.2016.10.3.313 | Intervention/Exposure
2590 | Yang, M, Gao, X, Xie, L, et al. Causal associations between dietary habits and CVD: a Mendelian randomisation study. British Journal of Nutrition. Dec 28 2023;130(12):2104-2113. doi:10.1017/S000711452300140x | Study design; Outcome
2591 | Yang, Q, Lin, SL, Au Yeung, SL, et al. Genetically predicted milk consumption and bone health, ischemic heart disease and type 2 diabetes: a Mendelian randomization study. Eur J Clin Nutr. 2017. 71:1008-1012. doi:10.1038/ejcn.2017.8 | Intervention/Exposure; Comparator
2592 | Yang, Y, Piao, W, Cai, S, et al. Comparison of data-driven identified hypertensionprotective dietary patterns among Chinese adults: based on a nationwide study. European Journal of Nutrition. Oct 2023;62(7):2805-2825. doi:10.1007/s00394-023-03195-9 | Intervention/Exposure
2593 | Yang, Y, Yu, D, Piao, W, et al. Nutrient-Derived Beneficial for Blood Pressure Dietary Pattern Associated with Hypertension Prevention and Control: Based on China Nutrition and Health Surveillance 2015-2017. Nutrients. 2022. 14(15). doi:10.3390/nu14153108 | Study design; Intervention/Exposure
2594 | Yang, Z, Yang, K, Zhang, X, et al. Dietary Saturated, Monounsaturated, or Polyunsaturated Fatty Acids and Estimated 10-Year Risk of a First Hard Cardiovascular Event. American Journal of Medicine. 2023. 136:796. doi: 10.1016/j.amjmed.2023.03.035 | Study design; Intervention/Exposure
2595 | Yannakoulia, M, Panagiotakos, D, Pitsavos, C, et al. Eating patterns may mediate the association between marital status, body mass index, and blood cholesterol levels in apparently healthy men and women from the ATTICA study. Soc Sci Med. 2008;66(11):2230-2239. doi:10.1016/j.socscimed.2008.01.051 | Study design; Intervention/Exposure
2596 | Yao, X, Xu, X, Wang, S, et al. Associations of Dietary Fat Intake With Mortality From All Causes, Cardiovascular Disease, and Cancer: A Prospective Study. Front Nutr. 2021. 8:701430. doi:10.3389/fnut.2021.701430 | Intervention/Exposure
2597 | Yap, J, Ng, HM, Peddie, MC, et al. How Does Being Overweight Moderate Associations between Diet and Blood Pressure in Male Adolescents?. Nutrients. 2021. 13. doi:10.3390/nu13062054 | Study design
2598 | Yap, RW, Shidoji, Y, Hon, WM, et al. Association and interaction between dietary pattern and VEGF receptor-2 (VEGFR2) gene polymorphisms on blood lipids in Chinese Malaysian and Japanese adults. Asia Pac J Clin Nutr. 2012. 21:302-11. | Study design
2599 | Yardimci, H, Ozcelik, AO, Surucuoglu, MS, et al. Relationship between hypertension and consumption frequency of certain foods. Pakistan Journal of Nutrition. 2015. 14:94-99. doi:10.3923/pjn.2015.94.99 | Study design
2600 | Yarnell, JWG, Fehily, AM, Gilbert, JF, et al. Effects of diet on blood lipid levels: Western-type diet and ‘prudent’ diet compared. J Human Nutr Diet. 1990. doi:10.1111/j.1365-277X.1990.tb00066.x | Intervention/Exposure; Sample size/Power
2601 | Yazdanpanah Z, Salehi-Abargouei A, Mollahosseini M, Sheikhha MH, Mirzaei M, Mozaffari-Khosravi H. The cluster of differentiation 36 (CD36) rs1761667 polymorphism interacts with dietary patterns to affect cardiometabolic risk factors and metabolic syndrome risk in apparently healthy individuals. Br J Nutr. 2023;130(9):1510-1520. | Study design
2602 | Yeh, CJ, Chang, HY, Pan, WH. Time trend of obesity, the metabolic syndrome and related dietary pattern in Taiwan: from NAHSIT 1993-1996 to NAHSIT 2005-2008. Asia Pacific journal of clinical nutrition. 2011. 20:292-300. | Study design; Intervention/Exposure
2603 | Yeo, R, Yoon, SR, Kim, OY. The Association between Food Group Consumption Patterns and Early Metabolic Syndrome Risk in Non-Diabetic Healthy People. Clin Nutr Res. 2017. 6:172-182. doi:10.7762/cnr.2017.6.3.172 | Study design
2604 | Yiannakou, I, Pickering, RT, Yuan, M, et al. Potato consumption is not associated with cardiometabolic health outcomes in Framingham Offspring Study adults. J Nutr Sci. 2022. 11:e73. doi:10.1017/jns.2022.65 | Intervention/Exposure
2605 | Yiannakou, I, Yuan, M, Zhou, X, et al. Dietary fat intakes, lipid profiles, adiposity, inflammation, and glucose in women and men in the Framingham Offspring Cohort. Front Physiol. 2023. 14:1144200. doi:10.3389/fphys.2023.1144200 | Intervention/Exposure
2606 | Yoko, J, Nanri, A, Eguchi, M, et al. Total, low-fat, and full-fat dairy consumption and risk of metabolic syndrome among workers. Clinical Nutrition ESPEN. 2021. 46:350-355. doi:10.1016/j.clnesp.2021.09.733 | Comparator
2607 | Yoshikawa, T, Kumagai, H, Myoenzono, K, et al. Effects of dietary modification with weight loss on central blood pressure during oral glucose tolerance test in overweight/obese men. Artery Research. Dec 2017;20:27-34. doi:10.1016/j.artres.2017.10.199 | Study design; Intervention/Exposure; Sample size/Power
2608 | You, W, Feng, S, Donnelly, F. Total meat (flesh) supply may be a significant risk factor for cardiovascular diseases worldwide. Food Sci Nutr. 2023. 11:3203-3212. doi:10.1002/fsn3.3300 | Study design; Intervention/Exposure
2609 | Young, AJ, Marriott, BP, Champagne, CM, et al. Blood fatty acid changes in healthy young Americans in response to a 10-week diet that increased n-3 and reduced n-6 fatty acid consumption: a randomised controlled trial. British Journal of Nutrition. May 2017;117(9):1257-1269. doi:10.1017/S0007114517001003 | Intervention/Exposure
2610 | Yu, D, Sonderman, J, Buchowski, MS, et al. Healthy Eating and Risks of Total and Cause-Specific Death among Low-Income Populations of African-Americans and Other Adults in the Southeastern United States: A Prospective Cohort Study. PLoS Med. 2015. 12:e1001830; discussion e1001830. doi:10.1371/journal.pmed.1001830 | Outcome
2611 | Yu, D, Zhang, X, Xiang, YB, et al. Adherence to dietary guidelines and mortality: A report from prospective cohort studies of 134,000 Chinese adults in urban Shanghai. American Journal of Clinical Nutrition. 2014. 100:693-700. doi:10.3945/ajcn.113.079194 | Intervention/Exposure; Country
2612 | Yu, G, Fu, H, Huang, W, et al. A Dietary Pattern of Higher Fish, Egg, Milk, Nut, Vegetable and Fruit, and Lower Salt Intake Correlates With the Prevalence and Control of Hypertension. Am J Hypertens. 2018. 31:679-686. doi:10.1093/ajh/hpy005 | Study design
2613 | Yuan, M, Singer, MR, Pickering, RT, et al. Saturated fat from dairy sources is associated with lower cardiometabolic risk in the Framingham Offspring Study. Am J Clin Nutr. 2022. 116:1682-1692. doi:10.1093/ajcn/nqac224 | Comparator
2614 | Yuan, S, Yu, HJ, Liu, MW, et al. Fat Intake and Hypertension Among Adults in China: The Modifying Effects of Fruit and Vegetable Intake. Am J Prev Med. 2020. 58:294-301. doi:10.1016/j.amepre.2019.09.004 | Intervention/Exposure; Country
2615 | Yubero-Serrano, EM, Delgado-Lista, J, Tierney, AC, et al. Insulin resistance determines a differential response to changes in dietary fat modification on metabolic syndrome risk factors: the LIPGENE study. Am J Clin Nutr. Dec 2015;102(6):1509-17. doi:10.3945/ajcn.115.111286 | Intervention/Exposure
2616 | Yun, H, Sun, L, Wu, Q, et al. Lipidomic Signatures of Dairy Consumption and Associated Changes in Blood Pressure and Other Cardiovascular Risk Factors Among Chinese Adults. Hypertension. Aug 2022;79(8):1617-1628. doi:10.1161/Hypertensionaha.122.18981 | Country
2617 | Yu-Poth, S, Etherton, TD, Reddy, CC, et al. Lowering dietary saturated fat and total fat reduces the oxidative susceptibility of LDL in healthy men and women. J Nutr. Sep 2000;130(9):2228-37. doi:10.1093/jn/130.9.2228 | Intervention/Exposure; Sample size/Power
2618 | Yuzbashian, E, Asghari, G, Mirmiran, P, et al. Changes in dairy product consumption and subsequent type 2 diabetes among individuals with prediabetes: Tehran Lipid and Glucose Study. Nutr J. 2021;20(1):88. Published 2021 Oct 29. doi:10.1186/s12937-021-00745-x | Outcome
2619 | Zarrazquin, I, Torres-Unda, J, Ruiz, F, et al. Longitudinal study: lifestyle and cardiovascular health in health science students. Nutr Hosp. Nov 1 2014;30(5):1144-51. doi:10.3305/nh.2014.30.5.7833 | Intervention/Exposure; No confounder adjustment
2620 | Zavos HMS, Riddleston L, Jayaweera K, et al. Frequency of Consumption of Food Groups and Cardio-Metabolic Risk Factors: A Genetically Informative Twin Study in Sri Lanka. Behav Genet. 2024;54(1):73-85. doi:10.1007/s10519-023-10165-8 | Study design
2621 | Zazpe, I, Sanchez-Tainta, A, Estruch, R, et al. A large randomized individual and group intervention conducted by registered dietitians increased adherence to Mediterranean-type diets: the PREDIMED study. J Am Diet Assoc. Jul 2008;108(7):1134-44; discussion 1145. doi:10.1016/j.jada.2008.04.011 | Intervention/Exposure
2622 | Zemel, MB, Donnelly, JE, Smith, BK, et al. Effects of dairy intake on weight maintenance. Nutr Metab (Lond). Oct 24 2008;5:28. doi:10.1186/1743-7075-5-28 | Intervention/Exposure; Comparator
2623 | Zemel, MB, Richards, J, Mathis, S, et al. Dairy augmentation of total and central fat loss in obese subjects. Int J Obes (Lond). 2005. 29:391-7. doi:10.1038/sj.ijo.0802880 | Intervention/Exposure; Comparator; Sample size/Power
2624 | Zhang T, Wang Q, Cui XM, et al. Mediating effect of cumulative lipid profile burden on the effect of diet and obesity on hypertension incidence: a cohort study of people aged 35-65 in rural China. Eur J Clin Nutr. 2024;78(1):54-63. doi:10.1038/s41430-023-01348-x | Comparator
2625 | Zhang, GL, Guo, G, Cheng, YP. Efficacy of early lifestyle intervention on metabolic syndrome. Biology. 2010. | Intervention/Exposure; Country
2626 | Zhang, H, Zeng, Y, Yang, H, et al. Familial factors, diet, and risk of cardiovascular disease: a cohort analysis of the UK Biobank. Am J Clin Nutr. Nov 8 2021;114(5):1837-1846. doi:10.1093/ajcn/nqab261 | Comparator
2627 | Zhang, J, Du, W, Huang, F, et al. Longitudinal study of dietary patterns and hypertension in adults: China Health and Nutrition Survey 1991-2018. Hypertens Res. 2023. 46:2264-2271. doi:10.1038/s41440-023-01322-x | Intervention/Exposure
2628 | Zhang, J, Hayden, K, Jackson, R, et al. Association of red and processed meat consumption with cardiovascular morbidity and mortality in participants with and without obesity: A prospective cohort study. Clin Nutr. 2021. 40:3643-3649. doi:10.1016/j.clnu.2020.12.030 | Comparator
2629 | Zhang, J, Kesteloot, H. Differences in all-cause, cardiovascular and cancer mortality between Hong Kong and Singapore: role of nutrition. European Journal of Epidemiology. 2001;17(5):469-477. doi:Doi 10.1023/A:1013773517052 | Study design; Intervention/Exposure
2630 | Zhang, J, Ping, W, Chunrong, W, et al. Nonhypercholesterolemic effects of a palm oil diet in Chinese adults. J Nutr. Mar 1997;127(3):509S-513S. doi:10.1093/jn/127.3.509S | Country
2631 | Zhang, J, Wang, C, Dai, J, et al. Palm oil diet may benefit mildly hypercholesterolaemic Chinese adults. Asia Pac J Clin Nutr. 1997. 6:22-5. | Country; Sample size/Power
2632 | Zhang, J, Wang, C, Li, L, et al. Dietary inclusion of salmon, herring and pompano as oily fish reduces CVD risk markers in dyslipidaemic middle-aged and elderly Chinese women. Br J Nutr. 2012. 108:1455-65. doi:10.1017/s0007114511006866 | Intervention/Exposure; Comparator
2633 | Zhang, J, Wang, CR, Xue, AN, et al. Effects of red palm oil on serum lipids and plasma carotenoids level in Chinese male adults. Biomed Environ Sci. Dec 2003;16(4):348-54 | Country; Sample size/Power
2634 | Zhang, J, Zhang, Y, Liu, L, et al. Associations between the timing of different foods’ consumption with cardiovascular disease and all-cause mortality among adults with sleep disorders. Front Nutr. 2022. 9:967996. doi:10.3389/fnut.2022.967996 | Intervention/Exposure; Comparator
2635 | Zhang, L, Sheng, J, Xuan, Y, et al. Undernutrition in childhood resulted in bad dietary behaviors and the increased risk of hypertension in a middle-aged Chinese population. J Dev Orig Health Dis. Oct 2018;9(5):544-551. doi:10.1017/S204017441800034X | Study design
2636 | Zhang, N, Xiao, X, Xu, J, et al. Dietary Approaches to Stop Hypertension (DASH) diet, Mediterranean diet and blood lipid profiles in less-developed ethnic minority regions. British Journal of Nutrition. 2022. 128:1137-1146. doi:10.1017/S0007114521004013 | Intervention/Exposure
2637 | Zhang, S, Stubbendorff, A, Ericson, U, et al. The EAT-Lancet diet, genetic susceptibility and risk of atrial fibrillation in a population-based cohort. BMC Medicine. 2023. 21(1):280. doi:10.1186/s12916-023-02985-6 | Outcome
2638 | Zhang, S, Li, H, Engström, G, et al. Milk intake, lactase persistence genotype, plasma proteins and risks of cardiovascular events in the Swedish general population. Eur J Epidemiol. 2023. 38:211-224. doi:10.1007/s10654-022-00937-7 | Intervention/Exposure; Comparator
2639 | Zhang, S, Zhuang, X, Lin, X, et al. Low-Carbohydrate Diets and Risk of Incident Atrial Fibrillation: A Prospective Cohort Study. J Am Heart Assoc. 2019. 8:e011955. doi:10.1161/jaha.119.011955 | Intervention/Exposure
2640 | Zhang, X, Qi, Q, Bray, GA, et al. APOA5 genotype modulates 2-y changes in lipid profile in response to weight-loss diet intervention: The Pounds Lost Trial. Am J Clin Nutr. Oct 2012;96(4):917-22. doi:10.3945/ajcn.112.040907 | Intervention/Exposure
2641 | Zhao, G, Etherton, TD, Martin, KR, et al. Dietary alpha-linolenic acid reduces inflammatory and lipid cardiovascular risk factors in hypercholesterolemic men and women. J Nutr. Nov 2004;134(11):2991-7. doi:10.1093/jn/134.11.2991 | Intervention/Exposure
2642 | Zhao, M, Chiriboga, D, Olendzki, B, et al. Substantial increase in compliance with saturated fatty acid intake recommendations after one year following the American heart association diet. Nutrients. Oct 12 2018;10(10)doi:10.3390/nu10101486 | Intervention/Exposure
2643 | Zhao, R, Zhao, L, Gao, X, et al. Geographic Variations in Dietary Patterns and Their Associations with Overweight/Obesity and Hypertension in China: Findings from China Nutrition and Health Surveillance (2015–2017). Nutrients. 2022. 14(19) doi:10.3390/nu14193949 | Study design
2644 | Zhao R, Zhao L, Yang F, et al. Dietary Fat Intake among Chinese Adults and Their Relationships with Blood Lipids: Findings from China Nutrition and Health Surveillance and Comparison with the PURE Study. Nutrients. 2022;14(24):5262. Published 2022 Dec 9. doi:10.3390/nu14245262 | Study design; Intervention/Exposure
2645 | Zhao, Y, Li, Y, Wang, W, et al. Low-carbohydrate diets, low-fat diets, and mortality in middle-aged and older people: A prospective cohort study. J Intern Med. Aug 2023;294(2):203-215. doi:10.1111/joim.13639 | Intervention/Exposure
2646 | Zhao, Y, Naumova, EN, Bobb, JF, et al. Joint Associations of Multiple Dietary Components With Cardiovascular Disease Risk: A Machine-Learning Approach. Am J Epidemiol. Jul 1 2021;190(7):1353-1365. doi:10.1093/aje/kwab004 | Study design
2647 | Zheng, C, Pettinger, M, Gowda, GAN, et al. Biomarker-Calibrated Red and Combined Red and Processed Meat Intakes with Chronic Disease Risk in a Cohort of Postmenopausal Women. J Nutr. 2022. 152:1711-1720. doi:10.1093/jn/nxac067 | Comparator
2648 | Zheng, H, Lorenzen, JK, Astrup, A, et al. Metabolic Effects of a 24-Week EnergyRestricted Intervention Combined with Low or High Dairy Intake in Overweight Women: An NMR-Based Metabolomics Investigation. Nutrients. 2016. 8:108. doi:10.3390/nu8030108 | Sample size/Power
2649 | Zheng, Y, Xu, X, Ye, W, et al. Dietary saturated fatty acids increased all-cause and cardiovascular disease mortality in an elderly population: The National Health and Nutrition Examination Survey. Nutr Res. Dec 2023;120:99-114. doi:10.1016/j.nutres.2023.10.002 | Intervention/Exposure
2650 | Zheng, Y, Li, Y, Satija, A, et al. Association of changes in red meat consumption with total and cause specific mortality among US women and men: two prospective cohort studies. Bmj. 2019. 365:l2110. doi:10.1136/bmj.l2110 | Outcome; Comparator
2651 | Zhong, GC, Hu, TY, Yang, PF, et al. Chocolate consumption and all-cause and cause-specific mortality in a US population: a post hoc analysis of the PLCO cancer screening trial. Aging (Albany NY). 2021. 13:18564-18585. doi:10.18632/aging.203302 | Comparator
2652 | Zhong, N, Han, P, Wang, Y, et al. Associations of polyunsaturated fatty acids with cardiovascular disease and mortality: a study of NHANES database in 2003?2018. BMC Endocrine Disorders. 2023. 23(1):185. doi:10.1186/s12902-023-01412-4 | Intervention/Exposure
2653 | Zhong, T, Huang, Y-Q, Wang, G-M. Causal relationship association of cheese intake with gestational hypertension and diabetes result from a Mendelian randomization study. World J Clin Cases. Oct 26 2023;11(30):7318-7328. doi:10.12998/wjcc.v11.i30.7318 | Outcome
2654 | Zhong, VW, Van Horn, L, Greenland, P, et al. Associations of Processed Meat, Unprocessed Red Meat, Poultry, or Fish Intake With Incident Cardiovascular Disease and All-Cause Mortality. JAMA Intern Med. 2020. 180:503-512. doi:10.1001/jamainternmed.2019.6969 | Comparator
2655 | Zhou, J, Wu, Z, Lin, Z, et al. Association of milk consumption with all-cause mortality and cardiovascular outcomes: a UK Biobank based large population cohort study. J Transl Med. 2023. 21:130. doi:10.1186/s12967-023-03980-4 | Comparator
2656 | Zhou, T, Li, X, Tang, Z, et al. Risk factors of CVD mortality among the elderly in Beijing, 1992 - 2009: an 18-year cohort study. Int J Environ Res Public Health. 2014. 11:2193-208. doi:10.3390/ijerph110202193 | Intervention/Exposure; Country
2657 | Zhu WL, Feng NP, Ma J, Wang Y, Ye GJ. [The effect of dietary intervention on lipidemia in school-aged children]. Zhonghua Liu Xing Bing Xue Za Zhi. Sep 2003;24(9):794-7. | Intervention/Exposure; Publication status
2658 | Zhu, J, Shi, Y, Wang, Y, et al. Effect of milk enriched with phytosterol ester on blood cholesterol of patients with hypercholesterolemia: a randomized controlled trial. Wei Sheng Yan Jiu. Sep 2016;45(5):718-732 | Publication language
2659 | Zhu, N, Yu, C, Guo, Y, et al. Adherence to a healthy lifestyle and all-cause and cause-specific mortality in Chinese adults: a 10-year prospective study of 0.5 million people. Int J Behav Nutr Phys Act. 2019. 16:98. doi:10.1186/s12966-019-0860-z | Country
2660 | Zhuang P, Cheng LF, Wang J, Zhang Y, Jiao JJ. Saturated Fatty Acid Intake Is Associated with Total Mortality in a Nationwide Cohort Study. Journal of Nutrition. Jan 2019;149(1):68-77. doi:10.1093/jn/nxy237 | Country
2661 | Zhuang P, Jiao J, Wu F, Mao L, Zhang Y. Associations of meat consumption and changes with all-cause mortality in hypertensive patients during 11.4-year follow-up: Findings from a population-based nationwide cohort. Clin Nutr. Mar 2021;40(3):1077-1084. doi:10.1016/j.clnu.2020.06.040 | Country
2662 | Zhuang P, Zhang Y, He W, et al. Dietary Fats in Relation to Total and Cause-Specific Mortality in a Prospective Cohort of 521 120 Individuals With 16 Years of Follow-Up. Circ Res. Mar 2019;124(5):757-768. doi:10.1161/CIRCRESAHA.118.314038 | Intervention/Exposure
2663 | Zibaeenezhad MJ, Shahamat M, Mosavat SH, Attar A, Bahramali E. Effect of Amygdalus scoparia kernel oil consumption on lipid profile of the patients with dyslipidemia: a randomized, open-label controlled clinical trial. Oncotarget. Oct 3 2017;8(45):79636-79641. doi:10.18632/oncotarget.18956 | Intervention/Exposure; Comparator
2664 | Zong G, Li Y, Sampson L, et al. Monounsaturated fats from plant and animal sources in relation to risk of coronary heart disease among US men and women. Am J Clin Nutr. Mar 1 2018;107(3):445-453. doi:10.1093/ajcn/nqx004 | Intervention/Exposure
2665 | Zong G, Sun Q, Yu D, et al. Dairy consumption, type 2 diabetes, and changes in cardiometabolic traits: a prospective cohort study of middle-aged and older Chinese in Beijing and Shanghai. Diabetes Care. 2014;37(1):56-63. doi:10.2337/dc13-0975 | Country
2666 | Zong G, Ye X, Sun L, et al. Associations of erythrocyte palmitoleic acid with adipokines, inflammatory markers, and the metabolic syndrome in middle-aged and older Chinese. Am J Clin Nutr. Nov 2012;96(5):970-6. doi:10.3945/ajcn.112.040204 | Intervention/Exposure; Country
2667 | Zubair N, Kuzawa CW, Lee NR, McDade TW, Adair LS. Clustering and determinants of cardiometabolic risk factors among Filipino young adults. Asia Pac J Clin Nutr. 2014;23(1):148-58. doi:10.6133/apjcn.2014.23.1.06 | Study design; Intervention/Exposure
2668 | Zubair N, Kuzawa CW, Lee NR, McDade TW, Adair LS. Clustering and determinants of cardiometabolic risk factors among Filipino young adults. Asia Pac J Clin Nutr. 2014;23(1):148-58. doi:10.6133/apjcn.2014.23.1.06 | Intervention/Exposure
2669 | Zujko ME, Rozniata M, Zujko K. Individual Diet Modification Reduces the Metabolic Syndrome in Patients Before Pharmacological Treatment. Nutrients. Jun 19 2021;13(6)doi:10.3390/nu13062102 | Intervention/Exposure
2670 | Zupo R, Sardone R, Donghia R, et al. Traditional Dietary Patterns and Risk of Mortality in a Longitudinal Cohort of the Salus in Apulia Study. Nutrients. Apr 12 2020;12(4)doi:10.3390/nu12041070 | Comparator
2671 | Zyriax BC, Boeing H, Windler E. Nutrition is a powerful independent risk factor for coronary heart disease in women-The CORA study: a population-based case-control study. Eur J Clin Nutr. Oct 2005;59(10):1201-7. doi:10.1038/sj.ejcn.1602233 | Study design