# Appendix 2 Literature search strategy

This search was first run on September 7, 2023, and then periodically run using NESR’s continuous evidence monitoring methods until January 2024.^*^

* USDA Nutrition Evidence Systematic Review Branch. Chapter 10: Continuous Evidence Monitoring. In: USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

[underlined: Database: PubMed]

Provider: U.S. National Library of Medicine

Date(s) Searched: September 7, 2023 (initial search); September 7, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 1990 - January 9, 2024

Table A 2 Search for PubMed

Search # | Concept | String
#1 | Food sources of saturated fats | “Dietary Fats”[Mesh:NoExp] OR “Fatty Acids”[Mesh:noexp] OR butter[tiab] OR lard[tiab] OR tallow[tiab] OR ghee[tiab] OR “Meat”[MeSH:NoExp] OR “Meat Products”[MeSH] OR “Meat Proteins”[MeSH] OR “Poultry”[MeSH] OR “Red Meat”[MeSH] OR meat*[tiab] OR beef[tiab] OR pork[tiab] OR sausage*[tiab] OR poultry[tiab] OR chicken[tiab] OR “Dairy Products”[Mesh] OR dairy[tiab] OR yogurt*[tiab] OR yoghurt*[tiab] OR milk*[tiab] OR “ice cream”[tiab] OR “sour cream”[tiab] OR “light cream”[tiab] OR “heavy cream”[tiab] OR “whipping cream”[tiab] OR “double cream”[tiab] OR “fat cream”[tiab] OR “half and half”[tiab] OR creamer[tiab] OR cheese*[tiab] OR chocolate*[tiab] OR “coconut*”[tiab] OR “palm oil*”[tiab] OR “palm olein*”[tiab] OR cocoa butter*[ tiab] OR “vegetable shortening”[tiab] OR “hydrogenated vegetable oil*”[tiab] OR “hydrogenated vegetable fat*”[tiab] OR crisco[tiab] OR ((fat[tiab] OR fats[tiab] OR fatty[tiab]) AND saturat*[tiab])
#2 | Cardiovascular risk and disease | “Cardiovascular Diseases”[Mesh:NoExp] OR “cardiovascular disease*”[tiab] OR “coronary artery disease”[tiab] OR “heart disease*”[tiab] OR “Heart Failure”[Mesh] OR “heart failure”[tiab] OR “myocardial infarction*”[tiab] OR “Myocardial Ischemia”[Mesh] OR “myocardial ischemia*”[tiab] OR “Stroke”[Mesh] OR “stroke*”[tiab] OR “angina”[tiab] OR “heart attack*”[tiab] OR “hypertension”[tiab] OR “Blood Pressure”[Mesh:NoExp] OR “high blood pressure”[tiab] OR “Lipids/blood”[Mesh] OR “Cholesterol, HDL”[Mesh] OR “HDL cholesterol”[tiab] OR “Cholesterol, LDL”[Mesh] OR “LDL cholesterol”[tiab] OR HDL[tiab] OR LDL[tiab] OR “blood cholesterol”[tiab] OR “Triglycerides”[Mesh] OR “triglycerides”[tiab] OR “Hypertension”[Mesh:NoExp] OR hypertensi*[tiab] OR Lipoprotein[tiab] OR “lipid profile*”[tiab] OR (Cardiovascular[tiab] AND risk*[tiab])
#3 | | #1 AND #2
#4 | Limits | #3 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Filters applied: English, from 1990/1/1 - 3000/12/12

[underlined: Database: Embase]

Provider: Elsevier

Date(s) Searched: September 7, 2023 (initial search); September 7, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 1990 - January 9, 2024

Table A 3 Search for Embase

Search # | Concept | String
#1 | Food sources of saturated fats | ‘Fat Intake’/de OR ‘Fatty Acids’/de OR ‘Saturated Fatty Acid’/exp OR ‘Meat’/de OR ‘Meat Protein’/exp OR ‘Processed Meat’/exp OR ‘Red Meat’/exp OR ‘Smoked Meat’/exp OR ‘White Meat’/exp OR ‘wild meat’/exp OR ‘Dairy Products’/exp OR butter:ab,ti OR lard:ab,ti OR tallow:ab,ti OR ghee:ab,ti OR meat*:ab,ti OR beef:ab,ti OR pork:ab,ti OR sausage*:ab,ti OR poultry:ab,ti OR chicken:ab,ti OR dairy:ab,ti OR yogurt*:ab,ti OR yoghurt*:ab,ti OR milk*:ab,ti OR “ice cream”:ab,ti OR “sour cream”:ab,ti OR “light cream”:ab,ti OR “heavy cream”:ab,ti OR “whipping cream”:ab,ti OR “double cream”:ab,ti OR “fat cream”:ab,ti OR “half and half”:ab,ti OR creamer:ab,ti OR cheese*:ab,ti OR chocolate*:ab,ti OR “coconut*”:ab,ti OR “palm oil*”:ab,ti OR “palm olein*”:ab,ti OR “cocoa butter* ”:ab,ti OR “vegetable shortening”:ab,ti OR “hydrogenated vegetable oil*”:ab,ti OR “hydrogenated vegetable fat*”:ab,ti OR crisco:ab,ti OR ((fat:ab,ti OR fats:ab,ti OR fatty:ab,ti) AND saturat*:ab,ti)
#2 | Cardiovascular risk and disease | ‘Cardiovascular Disease’/de OR ‘Heart Failure’/exp OR ‘heart muscle ischemia’/de OR ‘cerebrovascular accident’/exp OR ‘vein thrombosis’/exp OR ‘Blood Pressure’/de OR (‘Lipids’/exp AND ‘blood’:ab,ti) OR ‘high density lipoprotein cholesterol’/exp OR ‘low density lipoprotein cholesterol’/exp OR ‘hypertension’/exp OR ‘cardiovascular disease*’:ab,ti OR ‘coronary artery disease’:ab,ti OR ‘heart disease*’:ab,ti OR ‘heart failure’:ab,ti OR ‘myocardial infarction*’:ab,ti OR ‘myocardial ischemia*’:ab,ti OR ‘stroke*’:ab,ti OR ‘angina’:ab,ti OR ‘heart attack*’:ab,ti OR ‘hypertension’:ab,ti OR ‘high blood pressure’:ab,ti OR ‘HDL cholesterol’:ab,ti OR ‘LDL cholesterol’:ab,ti OR HDL:ab,ti OR LDL:ab,ti OR ‘blood cholesterol’:ab,ti OR ‘triglycerides’:ab,ti OR hypertensi*:ab,ti OR Lipoprotein:ab,ti OR “lipid profile*”:ab,ti OR (Cardiovascular:ab,ti AND risk*:ab,ti)
#3 | | #1 AND #2
#4 | Limits | #3 AND ([article]/lim OR [article in press]/lim); NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)); AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’:ab,ti OR ‘retraction notice’:ti OR ‘retracted publication’:ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR ‘practice guideline’:ti OR ‘protocol’:ti) AND [1990-2024]/py

[underlined: Database: Cochrane Central Register of Controlled Trials (CENTRAL)]

Provider: John Wiley & Sons

Date(s) Searched: September 7, 2023 (initial search); September 7, 2023 – January 9, 2024 (continuous evidence monitoring)

Dates Covered: January 1, 1990 - January 9, 2024

Table A 4 Search for Cochrane CENTRAL

Search # | Concept | String
#1 | Food sources of saturated fats | [mh ^“Dietary Fats”] OR [mh ^“Fatty Acids”] OR [mh ^“Meat”] OR [MH “Meat Products”] OR [MH “Meat Proteins”] OR [MH “Poultry”] OR [MH “Red Meat”] OR [MH “Dairy Products”] OR (butter OR lard OR tallow OR ghee OR meat* OR beef OR pork OR sausage* OR poultry OR chicken OR dairy OR yogurt* OR yoghurt* OR milk* OR “ice cream” OR “sour cream” OR “light cream” OR “heavy cream” OR “whipping cream” OR “double cream” OR “fat cream” OR “half and half” OR creamer OR cheese* OR chocolate* OR coconut* OR “palm oil” OR “palm oils” OR “palm olein” OR “palm oleins” OR “cocoa butter* ” OR “vegetable shortening” OR “hydrogenated vegetable oil” OR “hydrogenated vegetable oils” OR “hydrogenated vegetable fat” OR “hydrogenated vegetable fats” OR crisco OR ((fat OR fats OR fatty) AND saturat*)):ti,ab,kw
#2 | Cardiovascular risk and disease | [mh ^“Cardiovascular Diseases”] OR [mh “Heart Failure”] OR [mh “Myocardial Ischemia”] OR [mh “Stroke”] OR [mh ^“Blood Pressure”] OR [mh Lipids/BL] OR [mh “Cholesterol, HDL”] OR [mh “Cholesterol, LDL”] OR [mh “Triglycerides”] OR [mh ^“Hypertension”] OR (“cardiovascular disease” OR “cardiovascular diseases” OR “coronary artery disease” OR “heart disease” OR “heart diseases” OR “heart failure” OR “myocardial infarction” OR “myocardial infarctions” OR “myocardial ischemia” OR “myocardial ischemias” OR stroke* OR “angina” OR “heart attack” OR “heart attacks” OR “hypertension” OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR HDL OR LDL OR “blood cholesterol” OR “triglycerides” OR hypertensi* OR Lipoprotein OR “lipid profile” OR “lipid profiles” OR (Cardiovascular AND risk*)):ti,ab,kw
#3 | #1 AND #2 | In Trials, word variations searched; Year First Published: 1990-2024