# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body mass index
CHD: Coronary heart disease
CVD: Cardiovascular disease
FFQ: Food frequency questionnaire
HDL-C: High density lipoprotein-cholesterol
HHS: United States Department of Health and Human Services
LDL-C: Low density lipoprotein-cholesterol
MUFA: Monounsaturated fatty acids
NESR: Nutrition Evidence Systematic Review
PCS: Prospective Cohort Study
PUFA: Polyunsaturated fatty acids
RCT: Randomized controlled trial
SEP: Socioeconomic position
SFA: Saturated fatty acids
USDA: United States Department of Agriculture